# Thioridazine Therapy and CYP2D6 Genotypes

## Introduction

Thioridazine is an antipsychotic used in the treatment of schizophrenia and psychosis. Its use is reserved for individuals who have failed to respond to or cannot tolerate other antipsychotics due to the severity of its cardiac side effects. Thioridazine has been shown to prolong the QT interval (the time taken for the heart ventricles to depolarize and repolarize) in a dose related manner. Drugs with this potential have been associated with the life-threatening ventricular tachycardia, “Torsades de pointes” (1).

The CYP2D6 enzyme is involved in metabolizing thioridazine. Approximately 7% of the population has reduced enzyme activity because of variants in the CYP2D6 gene. In individuals with decreased CYP2D6 activity, standard doses of thioridazine may lead to higher drug levels in the plasma and increase the risk of cardiac arrhythmias. The FDA-approved drug label for thioridazine states that thioridazine is contraindicated in individuals who are known to have reduced levels of CYP2D6 activity (Table 1). The label also states it is contraindicated to administer thioridazine with drugs that inhibit CYP2D6 (for example, fluoxetine or paroxetine) or inhibit the metabolism of thioridazine (such as fluvoxamine, propranolol, and pindolol) (1). Drug repurposing studies have investigated the utility of thioridazine in various infectious diseases or as an adjuvant therapy in oncology, though the side effects of thioridazine and its dependence upon CYP2D6 in these uses has not yet been examined.

Table 1.

Recommendations for Thioridazine Based on CYP2D6 Status, FDA 2024

CYP2D6 status | Clinical impact | Recommendations
Reduced CYP2D6 activity (genetic or pharmacologic) | Elevated levels of thioridazine would be expected to augment the prolongation of the QTc interval; may increase the risk of serious, potentially fatal, cardiac arrhythmias, such as Torsades de pointes type arrhythmias. | Thioridazine is contraindicated.

Tabled adapted from (1).

## Drug Class: Antipsychotics

The first antipsychotics to be discovered in the 1950s were haloperidol and chlorpromazine, followed by other agents, including fluphenazine, loxapine, perphenazine, pimozide, thioridazine, thiothixene, and trifluoperazine.

Known as “first generation” or “typical” antipsychotics, these drugs were used to treat psychosis (regardless of the cause), chronic psychotic disorders (such as schizophrenia), and other psychiatric conditions. However, prominent adverse effects included extrapyramidal side effects such as tardive dyskinesia, muscle rigidity, and tremors, also called Parkinsonian-like symptoms.

Newer antipsychotics, known as “second generation” or “atypical” antipsychotics, have a lower risk of extrapyramidal side effects. However, many have serious metabolic effects. These antipsychotics include aripiprazole, clozapine, iloperidone, olanzapine, and risperidone.

## Drug: Thioridazine

Thioridazine is a first generation “typical” antipsychotic used in the treatment of schizophrenia. Schizophrenia is a severe neurodevelopmental disorder with a worldwide prevalence of around 0.3–0.7% (2, 3). The etiology of schizophrenia is unknown, but it is thought to result from a combination of complex genetic and environmental factors. Before the discovery of the first antipsychotics in the 1950s, the management of schizophrenia relied heavily upon sedation, electroconvulsive therapy, and institutionalization.

The symptoms of schizophrenia fall into 3 main categories: positive, negative, and cognitive. Positive symptoms are generally not found in healthy individuals but may come and go or persist in individuals with schizophrenia. Positive symptoms include reality distortion (for example, delusions, hallucinations) and thought disorders. These symptoms often respond well to treatment. Negative symptoms are deficits in normal emotions and behavior and may be mistaken for depression. Symptoms are divided into reduced expression of emotion (for example, speaking without moving or with a monotonous voice) and avolition (a lack of motivation to start or continue with a task). No treatment has established efficacy for these pathologies (4). Cognitive symptoms may also be difficult to recognize. They include poor executive functioning (understanding information and using it to make decisions) and trouble focusing or paying attention. Again, no treatment has established efficacy (5).

The use of thioridazine is reserved for individuals who have failed to respond to or cannot tolerate the side effects of other antipsychotics. The FDA-approved drug label for thioridazine strongly recommends that prior to starting thioridazine, an individual should be given at least 2 trials, each with a different antipsychotic drug product, at an adequate dose, for an adequate duration of time. The label also states that for individuals who do require chronic treatment with thioridazine, the smallest dose and the shortest duration of treatment should be sought and the need for continued treatment should be reassessed periodically; and cautions that the efficacy of thioridazine in treating individuals with refractory schizophrenia is unknown (1). Adult dosing should be initiated at 50 to 100 mg 3 times per day and gradually increased as indicated up to a maximum of 800 mg per day; maintenance dosing requirements may be lower than what is initially required to achieve efficacy (1, 6). When indicated in pediatric individuals, initial dose is 0.5 mg/kg/day in divided doses and a maximum of 3 mg/kg/day (1).

The main action of both first-generation and second-generation antipsychotics appears to be the post-synaptic blockade of D2 dopamine receptors in the brain. One exception is aripiprazole, which is a D2 partial agonist. Blockade of the D2 receptor in the brain’s limbic system is thought to improve the “positive” symptoms of schizophrenia (6, 7). Thioridazine is metabolized by CYP2D6 to the active metabolite mesoridazine, which is further metabolized to sulforidazine, both of which are more potent than thioridazine. In addition, both thioridazine and mesoridazine have similar effects on the QT interval (8, 9).

However, because the first-generation antipsychotics also block dopamine receptors in the nigrostriatal pathway, they cause movement disorders known as extrapyramidal side effects. These disorders include akathisia (motor restlessness), dystonia (abnormal muscle tone), and tardive dyskinesia (involuntary and repetitive movements). Dystonia may put the individual at risk for laryngospasm and difficulty breathing while TD can affect the head, tongue, or face and is largely irreversible (6). If an individual begins to develop TD, the best course is to discontinue thioridazine and substitute an atypical antipsychotic (6). Thioridazine discontinuation may cause withdrawal syndrome, which includes symptoms such as insomnia, anxiety and depression (10). Compared to other first-generation antipsychotics, thioridazine shares a similar efficacy, but has a lower risk of extrapyramidal side effects (11, 12, 13).

Antipsychotics, and thioridazine in particular, can inhibit cardiac ion channels. Most first-generation antipsychotics block the cardiac potassium channel KCNH2, previously known as the human ether-a-go-go-related gene (hERG) (14, 15). Blockade of this channel reduces inward potassium current, resulting in longer cardiac repolarization times. On the ECG, this manifests as a prolonged QT interval. In extreme cases, this can lead to a life-threatening ventricular tachycardia known as Torsades de pointes (“twisting of the points”) (16, 17, 18). A higher level of ECG changes is associated with thioridazine therapy compared with other first-generation antipsychotics (13). Thioridazine should not be used with other drugs that can prolong the QT interval or in individuals with congenital prolongation of the QT interval (1). Despite this warning, there is evidence from Thailand of co-prescription of thioridazine with QT prolonging medications (19).

At one point, thioridazine was one of the most used medications for major mental health disorders. However, numerous case reports of sudden, unexpected death led to label changes in 2000, which recommended that thioridazine be used as a last resort (20). In 2005, the manufacturer Novartis discontinued the branded form of thioridazine because of its association with QT prolongation, but generic forms are still available in the US (21, 22). Thioridazine, along with other antipsychotics, have a high risk of poisoning due to accidental ingestion or intentional overdose. Guidelines to manage overdose are included in the FDA approved label as well as additional resources (1, 23).

Additional side effects are detailed in the drug package insert and can include cutaneous photosensitivity (24), pigmentary retinopathy (25), and hepatotoxicity (1, 26, 27). An analysis of a national adverse event reporting database found no significant differences between women and men with regards to reporting odds for any of the major adverse reactions associated with first generation antipsychotics (28).

The FDA drug label states that no teratogenic effect has been shown with thioridazine to date. However, all drugs should be kept to a minimum during pregnancy, so thioridazine should be given only when the benefits exceed the possible risks to mother and fetus. Of note, neonates exposed to antipsychotic drugs during the third trimester are at risk for extrapyramidal, withdrawal symptoms, or both following delivery. In some cases symptoms have been self-limited, in other cases neonates have required intensive care unit support and prolonged hospitalization. (1)

There is limited information regarding use of thioridazine during breastfeeding, thus an alternate drug may be preferred, particularly for a newborn or preterm infant (29). Phenothiazines, including thioridazine, cause galactorrhea in more than a quarter of female individuals, likely due to increased serum prolactin levels; it is unknown how thioridazine may impact prolactin levels in a mother with established lactation (1, 29). The FDA-approved label states that antipsychotics are known to elevate prolactin levels and this may be important when considering this drug class for an individual with a history of breast cancer, since approximately one-third of breast cancers demonstrate in vitro dependence on prolactin (1). The clinical significance of elevated prolactin levels is unclear and epidemiological studies have not consistently shown association between hyperprolactinemia and breast cancer (1).

Thioridazine is not approved for treatment of individuals with dementia-related psychosis due to the increased risk of death in elderly individuals, secondary to cerebrovascular events (1, 6). Thioridazine has been used in pediatric behavioral disorders and pediatric weight-based dosing is included in the FDA-approved labeling (1, 6).

Recent research has found that thioridazine is active against multidrug resistant tuberculosis, when used in combination with antituberculosis drugs. Thioridazine increases the permeability of the cell-envelope, enabling the enhanced uptake of antibiotics (30). Additional studies have shown thioridazine has antimicrobial activity against Staphylococcus aureus and Listeria monocytogenes at clinically relevant doses (31). Drug-repurposing studies have also investigated the utility of thioridazine and other antipsychotics in gastric cancer (32), osteosarcoma (33), and other in vitro cancer models (34) as well as infectious diseases including leishmaniasis (35). Large, retrospective studies have not consistently indicated that thioridazine therapy may reduce the risk of cancer (36, 37), indicating more research is needed.

## Gene: CYP2D6

The cytochrome P450 superfamily (CYP450) is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are highly polymorphic and can result in decreased, absent, or increased enzyme activity. One prominent member, CYP2D6, is responsible for metabolizing many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### The CYP2D6 Alleles

The CYP2D6 gene is highly polymorphic, as over 180 star (*) alleles have been described and cataloged at the Pharmacogene Variation (PharmVar) Consortium, and each allele is associated with either normal, decreased, or absent enzyme function (Table 2) (38, 39). Star alleles are defined by the variants detected on one chromosome (haplotype).

The combination of CYP2D6 haplotypes that a person has is used to determine their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele can be assigned an activity score from 0 to 1, which in turn is then used to assign a phenotype of metabolizer status (for example, CYP2D6 poor metabolizer). The activity score system is not standardized across all clinical laboratories or CYP2D6 genotyping platforms, leading to variability among results. To promote harmonization, the Clinical Pharmacogenetics Implementation Consortium (CPIC) and Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Pharmacist's Association created a consensus activity score guideline for CYP2D6 phenotype. The CYP2D6 phenotype is predicted from the diplotype activity score defined by the sum of the allele score values, including deletions or duplications, which usually ranges from 0 to 3.0: (40)

- An ultrarapid metabolizer (UM) has an activity score greater than 2.25
- A normal metabolizer (NM) has an activity score of 1.25–2.25
- An intermediate metabolizer (IM) has an activity score of >0–<1.25
- A poor metabolizer (PM) has an activity score of 0

Table 2.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *27, *33 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6) and (39). Activity scores from (40).

The CYP2D6*1 allele is the wild-type allele, detected when no variants are present, and is associated with normal enzyme activity and the NM phenotype. The CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, and *6) (41, 42, 43) or an enzyme with decreased activity (for example, *10, *17, and *41) (44, 45) (see Table 2). There are significant interethnic differences in the frequency of these alleles. For example, *3, *4, *6, and *41 are more common in individuals of European ancestry, *17 is more common in African ancestry, and *10 is more common in Asian ancestry. (46)

Larger structural variants at the CYP2D6 locus have also been described, including gene duplications, deletions, tandem alleles, gene hybrids (namely, CYP2D6-CYP2D7), and gene conversions. As expected, deletions result in a no-function allele (for example, the *5 allele is a deletion). Duplications have been reported for alleles with normal function and decreased function. In cases of allele duplications, the activity scores for the full complement of CYP2D6 alleles are summed to determine the predicted metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (47).

The frequency of the CYP2D6 star alleles with altered function varies across global populations, resulting in different frequencies of the resulting metabolizer phenotypes. Given CYP2D6’s role in the metabolism of many drugs, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency for normal-function star alleles, and thus a high proportion of the population are NMs. However, decreased-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, leading to a higher proportion of IM phenotype individuals in this ancestral group. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, which can correlate with lower metabolizer scores in these individuals. The frequency of UM is notably high in northern Africa, particularly in Algeria, mestizo Columbian population, the Druze ancestry group from the Middle East, and non-Austronesian Melanesian populations (48, 49). Given the distribution of duplicated, functional CYP2D6 alleles, some have proposed that a gene duplication event arose in populations based in the region of Saudi Arabia-Ethiopia, then spread through migration along the Mediterranean, resulting in a higher frequency of UM phenotype in the ancestral populations from these regions (50, 51). More details regarding published allele and phenotype frequencies are available in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Factors other than genotype can influence CYP2D6 enzyme activity and, consequently, the metabolizer phenotype of any individual. The administration of an interacting medication can lead to a phenomenon called phenoconversion, wherein an individual with one metabolizer genotype exhibits the enzymatic activity of a different metabolizer group (higher or lower, depending on the medications).

The enzymatic activity of CYP2D6 can be inhibited or reduced by medications, including strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, as well as moderate inhibitors like duloxetine (52, 53, 54). This can potentially result in NMs or IMs to respond to medications as if they were PMs, depending on the strength of the enzyme inhibition. Strong inhibitors can completely inhibit CYP2D6 activity, while moderate inhibitors can reduce activity by 50%. Consequently, co-medication with multiple CYP2D6 strong or moderate inhibitors may result in reduced metabolism of drug substrates, as has been observed in psychiatric pharmacotherapy (55, 56). In contrast, discontinuing a concomitant CYP2D6 inhibitor can restore the individual's CYP2D6 activity to their genetically predicted phenotype baseline. Integration of CYP2D6 phenoconversion into clinical practice requires knowledge of multiple clinical factors. Tools have been developed to support clinicians in this process (57).

## Linking Genetic Variation with Treatment Response

The FDA-approved drug label states that CYP2D6 PM status or CYP2D6 inhibitor co-medications are contraindications for thioridazine (1). Other medications can also inhibit CYP2D6 metabolism of thioridazine and are contraindicated with thioridazine: fluvoxamine, propranolol, and pindolol (1). The number of functional CYP2D6 alleles inversely correlates with dose-corrected thioridazine plasma levels (58), with PMs experiencing significantly higher dose-corrected plasma levels than other metabolizer groups (59).

Higher plasma levels of thioridazine are “expected to augment the prolongation of the QTc interval and may increase the risk of serious, potentially fatal, cardiac arrhythmias, such as Torsades de pointes type arrhythmias” (1). Side effects such as ocular toxicity are typically reported at dosages greater than 800 mg/day for a prolonged course, though toxicity at 100 mg per day has also been reported (25). Thus, it is possible that CYP2D6 PM (either genetic or due to phenoconversion) may be at higher risk for additional adverse reactions due to higher plasma concentrations of thioridazine at standard doses.

## Genetic Testing

The NIH’s Genetic Testing Registry (GTR) lists genetic tests available for thioridazine response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN078018) and the CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5Bgeneid%5D). The available CYP2D6 tests include targeted single-gene tests as well as multi-gene panels. In addition, variant CYP2D6 alleles to be included in clinical genotyping assays have been recommended by the Association for Molecular Pathology (AMP) (60). For CYP2D6, the AMP recommends the minimum panel of variant alleles should include *2, *3, *4, *5, *6, *9, *10, *17, *29, *41, and copy number interrogation.

Results are typically reported as a diplotype, such as CYP2D6 *1/*1 (wild-type). A result for copy number, if available, is also important when interpreting CYP2D6 results (61, 62). When individuals have more than 2 copies of CYP2D6, the copies of the allele are denoted by an “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6*1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use the notation of DUP to indicate an increase in copy number, but the report does not always specify the number of duplications nor the allele that has been duplicated due to technical limitations. The test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be confirmed by checking the diplotype and calculating the CYP2D6 activity score, as described in the “CYP2D6 Alleles” section above.

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in a real-world clinical setting (63, 64, 65). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, where gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (66).

## The CYP2D6 Gene Interactions with Medications Used for Additional Indications

The CYP family of enzymes is involved in the metabolism of many substances and CYP2D6 especially has been implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

- Cardiovascular diseases—for example, metoprolol, carvedilol, and propafenone are used to manage arrhythmias or heart failure and changes in CYP2D6 activity can impact the levels of these medications.
- Tricyclic antidepressants—for example, amitriptyline, and imipramine may require an alternative therapy or dosage adjustments, potentially guided by therapeutic drug monitoring, to achieve the desired therapeutic range in UMs or PMs. Ultimately, tricyclic antidepressants may be ineffective in CYP2D6 UMs, depending upon the indication and dosage used.
- Serotonin and norepinephrine reuptake inhibitors—for example atomoxetine and venlafaxine may have reduced efficacy in UMs at standard doses while PMs are at risk of elevated plasma concentrations for both medications. The Dutch Pharmacogenetics Working Group advises against the use of venlafaxine in CYP2D6 PMs and IMs.
- Anticancer medications—for example, tamoxifen is activated by CYP2D6, and IMs or PMs may have reduced benefit from tamoxifen therapy.
- Pain management—for example, codeine and tramadol are pro-drugs that require activation by CYP2D6 to achieve the desired analgesic effect.
- Antimalarial medications—for example, primaquine must be metabolized by CYP2D6 to form the hydroxylated active metabolite that targets the parasite.
- Various therapies for genetic disorders—for example eliglustat used in the treatment of Gaucher disease, and deutetrabenazine and valbenazine used in the treatment of Huntington disease and tardive dyskinesia—have reduced dose recommendations for CYP2D6 PMs. The CYP2D6 UMs may not achieve adequate concentrations of eliglustat and therefore CYP2D6 genotyping is required before initiation of eliglustat therapy.

It is important to note that CYP2D6 is the most common biomarker in drug responses for FDA drug labels; the list provided here is by no means exhaustive. Additional information on gene-drug interactions for CYP2D6 are available from ClinPGx (https://www.clinpgx.org/gene/PA128), CPIC (https://cpicpgx.org/genes-drugs/) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA): Reduced cytochrome P450 2D6 isozyme activity drugs that inhibit this isozyme (e.g., fluoxetine and paroxetine) and certain other drugs (e.g., fluvoxamine, propranolol, and pindolol) appear to appreciably inhibit the metabolism of thioridazine. The resulting elevated levels of thioridazine would be expected to augment the prolongation of the QTc interval associated with thioridazine and may increase the risk of serious, potentially fatal, cardiac arrhythmias, such as Torsades de pointes type arrhythmias. Such an increased risk may result also from the additive effect of coadministering thioridazine with other agents that prolong the QTc interval. Therefore, thioridazine is contraindicated with these drugs as well as in patients, comprising about 7% of the normal population, who are known to have a genetic defect leading to reduced levels of activity of P450 2D6.

Please review the complete therapeutic recommendations that are located here: (1).

## Nomenclature of selected CYP2D6 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A+1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (67)

^[2]^ AMP Tier 2 allele, (67)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (68).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (69).

## Acknowledgments

Version 1, Published February 9, 2017:

The author would like to thank David Kisor, B.S., Pharm.D., Professor and Director of Pharmacogenomics Education, Pharmacogenomics Program, Manchester University, Indiana; Mohamed Nagy, Clinical Pharmacist, Head of the Personalised Medication Management Unit, Department of Pharmaceutical Services, Children's Cancer Hospital, Egypt; and Yolande Saab, Pharm.D., Ph.D., Associate Professor of Pharmacogenomic, School of Pharmacy, Lebanese American University, Lebanon; for reviewing this summary.

Version 2.0, Published December 18, 2025:

The author would like to acknowledge Natasha Petry, PharmD, MPH, BCACP, Associate Professor, North Dakota State University, Fargo, ND, USA, and Clinical Pharmacist, Sanford Health Imagenetics, Sioux Falls, SD, USA and Zachary Woodward, PharmD, Commander U.S. Public Health Service, U.S. Coast Guard Base Los Angeles- Long Beach, CA, USA for reviewing this summary.

## Version History

Version 1 of this summary, published on February 9, 2017, is available here.

Version 2.0 of this summary was published on December 18, 2025. There is no change in regulatory prescribing recommendations relative to version 1.0.

Version 2.1 of this summary was published on January 14, 2026 to correct the URL for a citation.

## References

1 THIORIDAZINE HYDROCHLORIDE tablet, film coated. Morgantown, WV, USA: Mylan Pharmaceuticals Inc.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=56b3f4c2-52af-4947-b225-6808ae9f26f5.
2 van Os, J. and S. Kapur, Schizophrenia. Lancet, 2009. 374(9690): p. 635–45.19700006
3 Moreno-Kustner, B., C. Martin, and L. Pastor, Prevalence of psychotic disorders and its association with methodological issues. A systematic review and meta-analyses. PLoS One, 2018. 13(4): p. e0195687.29649252
4 Moccia, L., F. Bardi, M.B. Anesini, S. Barbonetti, et al., Pharmacological Interventions for Negative Symptoms in Schizophrenia: A Systematic Review of Randomised Control Trials. Biomedicines, 2025. 13(3).40149518
5 Feber, L., N.L. Peter, V. Chiocchia, J. Schneider-Thoma, et al., Antipsychotic Drugs and Cognitive Function: A Systematic Review and Network Meta-Analysis. JAMA Psychiatry, 2025. 82(1): p. 47–56.39412783
6 Feinberg, S.M., K.A. Fariba, and A. Saadabadi, Thioridazine, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/29083818.
7 Goodnick, P.J. and J.M. Jerry, Aripiprazole: profile on efficacy and safety. Expert Opin Pharmacother, 2002. 3(12): p. 1773–81.12472374
8 Dorado, P., L.E.M. Penas, A. de la Rubia, and L.L. A, Relevance of CYP2D6 -1584C>G polymorphism for thioridazine:mesoridazine plasma concentration ratio in psychiatric patients. Pharmacogenomics, 2009. 10(7): p. 1083–9.19604081
9 Salih, I.S., R.H. Thanacoody, G.A. McKay, and S.H. Thomas, Comparison of the effects of thioridazine and mesoridazine on the QT interval in healthy adults after single oral doses. Clin Pharmacol Ther, 2007. 82(5): p. 548–54.17410120
10 Storck, W., T.T. de Laportaliere, A. Yrondi, H. Javelot, et al., Withdrawal syndrome after antipsychotics discontinuation: an analysis of the WHO database of spontaneous reports (Vigibase) between 2000 and 2022. Psychopharmacology (Berl), 2024. 241(6): p. 1205–1212.38376511
11 Yang, S.Y., Y.H. Kao Yang, M.Y. Chong, Y.H. Yang, et al., Risk of extrapyramidal syndrome in schizophrenic patients treated with antipsychotics: a population-based study. Clin Pharmacol Ther, 2007. 81(4): p. 586–94.17235331
12 Thanacoody, H.K., Thioridazine: resurrection as an antimicrobial agent? Br J Clin Pharmacol, 2007. 64(5): p. 566–74.17764469
13 Fenton, M., J. Rathbone, J. Reilly, and A. Sultana, Thioridazine for schizophrenia. Cochrane Database Syst Rev, 2007(3): p. CD001944.17636691
14 Oshiro, C., C.F. Thorn, D.M. Roden, T.E. Klein, et al., KCNH2 pharmacogenomics summary. Pharmacogenet Genomics, 2010. 20(12): p. 775–7.20150828
15 Reilly, J.G., S.A. Ayis, I.N. Ferrier, S.J. Jones, et al., QTc-interval abnormalities and psychotropic drug therapy in psychiatric patients. Lancet, 2000. 355(9209): p. 1048–52.10744090
16 Crumb, W.J., Jr., S. Ekins, R.D. Sarazan, J.H. Wikel, et al., Effects of antipsychotic drugs on I(to), I (Na), I (sus), I (K1), and hERG: QT prolongation, structure activity relationship, and network analysis. Pharm Res, 2006. 23(6): p. 1133–43.16715368
17 Berling, I. and G.K. Isbister, Prolonged QT Risk Assessment in Antipsychotic Overdose Using the QT Nomogram. Ann Emerg Med, 2015. 66(2): p. 154–64.25639523
18 Kongsamut, S., J. Kang, X.L. Chen, J. Roehr, et al., A comparison of the receptor binding and HERG channel affinities for a series of antipsychotic drugs. Eur J Pharmacol, 2002. 450(1): p. 37–41.12176106
19 Waleekhachonloet, O., C. Limwattananon, and T. Rattanachotphanit, Coprescription of QT interval-prolonging antipsychotics with potentially interacting medications in Thailand. Ther Adv Drug Saf, 2019. 10: p. 2042098619854886.31223470
20 Ray, W.A. and K.G. Meador, Antipsychotics and sudden death: is thioridazine the only bad actor? Br J Psychiatry, 2002. 180: p. 483–4.12042224
21 THIORIDAZINE - Withdrawn due to poor benefit/risk profile. . WHO Pharmaceuticals Newsletter 2005 [cited 2025 June 2025]; Available from: https://iris.who.int/bitstream/handle/10665/255787/WPN-2005-01-eng.pdf?sequence=1.
22 Purhonen, M., H. Koponen, J. Tiihonen, and A. Tanskanen, Outcome of patients after market withdrawal of thioridazine: a retrospective analysis in a nationwide cohort. Pharmacoepidemiol Drug Saf, 2012. 21(11): p. 1227–31.22941581
23 Euwema, M.S. and T.J. Swanson, Deadly Single Dose Agents, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/28722879.
24 Blakely, K.M., A.M. Drucker, and C.F. Rosen, Drug-Induced Photosensitivity-An Update: Culprit Drugs, Prevention and Management. Drug Saf, 2019. 42(7): p. 827–847.30888626
25 Corradetti, G., S. Violanti, A. Au, and D. Sarraf, Wide field retinal imaging and the detection of drug associated retinal toxicity. Int J Retina Vitreous, 2019. 5(Suppl 1): p. 26.31890286
26 Zeiss, R., S. Hafner, C. Schonfeldt-Lecuona, B.J. Connemann, et al., Drug-Associated Liver Injury Related to Antipsychotics: Exploratory Analysis of Pharmacovigilance Data. J Clin Psychopharmacol, 2022. 42(5): p. 440–444.35730552
27 Antipsychotic Agents, in LiverTox: Clinical and Research Information on Drug-Induced Liver Injury. 2012: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/31643640.
28 McCall, K.L., B.J. Doughty, B.J. Piper, H. Naik, et al., First generation antipsychotic-associated serious adverse events in women: a retrospective analysis of a pharmacovigilance database. Int J Clin Pharm, 2024. 46(2): p. 515–521.38315306
29 Thioridazine, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000170.
30 de Keijzer, J., A. Mulder, P.E. de Haas, A.H. de Ru, et al., Thioridazine Alters the Cell-Envelope Permeability of Mycobacterium tuberculosis. J Proteome Res, 2016. 15(6): p. 1776–86.27068340
31 Lorente-Torres, B., J. Llano-Verdeja, P. Castanera, H.A. Ferrero, et al., Innovative Strategies in Drug Repurposing to Tackle Intracellular Bacterial Pathogens. Antibiotics (Basel), 2024. 13(9).39335008
32 Amjadi, O., A. Hedayatizadeh-Omran, E. Zaboli, G. Janbabaei, et al., Revealing New Prospects: Antipsychotic Drugs Exert Anti-Tumor Effects against Gastric Cancer through Inducing Apoptosis. Curr Cancer Drug Targets, 2024.38984576
33 Camuzard, O., M.C. Trojani, S. Santucci-Darmanin, S. Pagnotta, et al., Autophagy in Osteosarcoma Cancer Stem Cells Is Critical Process which Can Be Targeted by the Antipsychotic Drug Thioridazine. Cancers (Basel), 2020. 12(12).33297525
34 Chou, M.Y. and S.Y. Lin-Shiau, Novel regimens of phytopolyphenols and celecoxib enhancing efficacy and selectivity of anticancer effects of chemotherapeutic agents on cultured cancer cells. J Dent Sci, 2024. 19(3): p. 1486–1498.39035282
35 Sifontes-Rodriguez, S., N. Mollineda-Diogo, L. Monzote-Fidalgo, A.R. Escalona-Montano, et al., In Vitro and In Vivo Antileishmanial Activity of Thioridazine. Acta Parasitol, 2024. 69(1): p. 324–331.38070122
36 Hsieh, Y.H., H.L. Chan, C.F. Lin, S.H. Liang, et al., Antipsychotic use is inversely associated with gastric cancer risk: A nationwide population-based nested case-control study. Cancer Med, 2019. 8(9): p. 4484–4496.31183993
37 Chang, C.C., M.H. Hsieh, J.Y. Wang, N.Y. Chiu, et al., Association between Thioridazine Use and Cancer Risk in Adult Patients with Schizophrenia-A Population-Based Study. Psychiatry Investig, 2018. 15(11): p. 1064–1070.30481993
38 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154–170.31544239
39 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399–401.29134625
40 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215–223.27441996
41 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256–63.8287064
42 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6–13.15492763
43 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*4 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816579.
44 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816582.
45 Gaedigk, A., K. Sangkuhl, M. Whirl-Carrillo, T. Klein, et al., Prediction of CYP2D6 phenotype from genotype across world populations. Genet Med, 2017. 19(1): p. 69–76.27388693
46 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229–43.11972444
47 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
48 Koopmans, A.B., M.H. Braakman, D.J. Vinkers, H.W. Hoek, et al., Meta-analysis of probability estimates of worldwide variation of CYP2D6 and CYP2C19. Transl Psychiatry, 2021. 11(1): p. 141.33627619
49 A, P.S., P. Dorado, A. Borbon, F. de Andres, et al., High prevalence of CYP2D6 ultrarapid metabolizers in a mestizo Colombian population in relation to Hispanic mestizo populations. Pharmacogenomics, 2020. 21(17): p. 1227–1236.
50 Ingelman-Sundberg, M., Pharmacogenetics: an opportunity for a safer and more efficient pharmacotherapy. J Intern Med, 2001. 250(3): p. 186–200.11555122
51 Aklillu, E., K. Herrlin, L.L. Gustafsson, L. Bertilsson, et al., Evidence for environmental influence on CYP2D6-catalysed debrisoquine hydroxylation as demonstrated by phenotyping and genotyping of Ethiopians living in Ethiopia or in Sweden. Pharmacogenetics, 2002. 12(5): p. 375–83.12142727
52 US FDA. Drug Development and Drug Interactions | Table of Substrates, Inhibitors and Inducers. 2023 5 June 2023 7 June 2024]; Available from: https://www.fda.gov/drugs/drug-interactions-labeling/drug-development-and-drug-interactions-table-substrates-inhibitors-and-inducers.
53 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842–1850.30670877
54 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933–939.29882961
55 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024. 29(11): p. 3495–3502.38783055
56 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
57 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677–687.34231197
58 Berecz, R., A. de la Rubia, P. Dorado, P. Fernandez-Salguero, et al., Thioridazine steady-state plasma concentrations are influenced by tobacco smoking and CYP2D6, but not by the CYP2C9 genotype. Eur J Clin Pharmacol, 2003. 59(1): p. 45–50.12682803
59 Thanacoody, R.H., A.K. Daly, J.G. Reilly, I.N. Ferrier, et al., Factors affecting drug concentrations and QT interval during thioridazine therapy. Clin Pharmacol Ther, 2007. 82(5): p. 555–65.17460606
60 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and the European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021. 23(9): p. 1047–1064.34118403
61 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127–34.25974703
62 Jarvis, J.P., A.P. Peter, and J.A. Shaman, Consequences of CYP2D6 Copy-Number Variation for Pharmacogenomics in Psychiatry. Front Psychiatry, 2019. 10: p. 432.31281270
63 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, et al., Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89–99.35194175
64 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094–3118.34474980
65 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347–356.36739136
66 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116–3125.37277227
67 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.34118403
68 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564–9.26931183
69 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, et al., Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542–545.34091888

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Aripiprazole Therapy and CYP2D6 Genotype

Atomoxetine Therapy and CYP2D6 Genotype

CYP2D6 Overview: Allele and Phenotype Frequencies

Carvedilol Therapy and CYP2D6 Genotype

Clozapine Therapy and CYP Genotype

Codeine Therapy and CYP2D6 Genotype

Deutetrabenazine Therapy and CYP2D6 Genotype

Eliglustat Therapy and CYP2D6 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Metoprolol Therapy and CYP2D6 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Primaquine Therapy and G6PD and CYP2D6 Genotype

Propafenone Therapy and CYP2D6 Genotype

Risperidone Therapy and CYP2D6 Genotype

Tamoxifen Therapy and CYP2D6 Genotype

Tramadol Therapy and CYP2D6 Genotype

Valbenazine Therapy and CYP2D6 Genotype

Venlafaxine Therapy and CYP2D6 Genotype

## Tests in GTR by Condition

Thioridazine response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN078018&term=CN078018[DISCUI]&display_string=Thioridazine response)

## Tests in GTR by Gene

CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1565[geneid]+AND+CN078018[cui])