# Sofosbuvir Therapy and IFNL4 Genotype

## Introduction

Sofosbuvir is an antiviral agent used in the treatment of chronic hepatitis C virus (HCV) infection. Sofosbuvir is FDA-approved to treat individuals infected with HCV genotypes 1, 2, 3, and 4, as part of a combination antiviral treatment regimen (1). The most prevalent genotype worldwide is HCV genotype 1, and HCV genotype 3 is the second most prevalent (2). Sofosbuvir may also be used as part of the treatment regimen of HCV genotypes 5 or 6 (3).

Approximately 180 million people worldwide are infected with chronic hepatitis C, which is a major cause of chronic liver disease, cirrhosis, and liver cancer. Viral eradication is suboptimal with peginterferon plus ribavirin-based therapy, with just under half of individuals with HCV genotype 1 infection achieving a sustained virological response (SVR) after 24 weeks (4). An SVR is defined as undetectable HCV RNA by the end of treatment or at a specific number of weeks after the initiation of treatment; for example, undetectable HCV RNA at 12 weeks is annotated as SVR12.

Direct-acting antivirals (DAAs), such as sofosbuvir, were developed to improve viral eradication rates. They target HCV-encoded proteins involved in viral replication and infection. Sofosbuvir, a key component of DAA regimens, targets NS5B polymerase, the viral enzyme required for HCV RNA replication.

Sofosbuvir may be used with peginterferon. The genetic variant rs12979860, located in the INFL4 gene, is a strong predictor of response to peginterferon-based therapies. The variant is a C to T change—individuals with the favorable “C/C” genotype have approximately a 2-fold higher likelihood of achieving SVR compared with individuals with CT or TT genotype (5). (Note, because the association of rs12979860 with treatment response was reported several years before the discovery of IFNL4, the variant is commonly referred to as IL28B, which was the previous name for the IFNL3 gene.)

For specific treatment regimens that include sofosbuvir, although the IFNL4 variant still influences treatment outcomes, the SVR remains relatively high for all IFNL4 genotypes. For example, in the NEUTRINO study, the SVR12 rate was 99% in individuals with baseline C/C alleles and 87% in individuals with non-C/C alleles. The individuals in this study had HCV genotype 1 or 4 infection and were receiving sofosbuvir plus peginterferon plus ribavirin therapy (1, 6).

The drug label for sofosbuvir also discusses viral resistance. In cell culture, the amino acid substitution S282T in the viral NS5B polymerase is associated with reduced susceptibility to sofosbuvir (1). During the ELECTRON trial, this substitution was transiently detected in one individual who relapsed during sofosbuvir monotherapy. However, the clinical significance of such substitutions remains unknown (1).

## Drug Class: Direct Acting Antivirals for HCV

The treatment of hepatitis C virus (HCV) has evolved over the years. Initially, interferon (IFN) was used as monotherapy. This was followed by the addition of the antiviral agent ribavirin (a nucleoside analogue) to peginterferon. However, only approximately half of the HCV genotype 1-infected individuals cleared their infection, and adverse effects were common and sometimes life-threatening (4). Treatment was also expensive and inconvenient, lasting up to 48 weeks.

Direct-acting antivirals (DAAs) improved the effectiveness of peginterferon and ribavirin therapy. These agents target specific viral proteins required for viral replication and infection.

HCV is a single-stranded RNA virus that encodes structural proteins (to encode the viral capsid and envelope) and non-structural proteins (required for viral replication). The DAAs target several of the non-structural proteins, the viral protease (NS3/NS4A), the viral RNA polymerase (NS5B), and a viral protein thought to regulate replication and viral assembly (NS5A).

There are 3 classes of drugs in clinical use or in development, which are classified by their therapeutic target:

- NS3/4 protease inhibitors such as asunaprevir, grazoprevir, paritaprevir, telaprevir, and voxilaprevir
- NS5B polymerase inhibitors such as sofosbuvir and dasabuvir
- NS5A inhibitors such as daclatasvir, elbasvir, ledipasvir, and pibrentasvir

There are also clinical indications for interferon-alpha and ribavirin to be added to the DAA medications (7). By combining multiple classes of DAAs or other medications, one treatment regimen can target multiple HCV genotypes or resistance-conferring mutations in HCV. Successful treatment of hepatitis C is confirmed when no trace of HCV can be found after treatment has finished. This is referred to as the SVR, which is defined as undetectable HCV RNA by a quantification assay at the end of treatment, and typically 12 (SVR12) or 24 (SVR24) weeks after the end of treatment.

## Drug: Sofosbuvir

Sofosbuvir is a nucleotide analogue used in the treatment of chronic HCV infection as part of a combination antiviral treatment regimen. Recommended regimens include glecaprevir with pibrentasvir, sofosbuvir with velpatasvir, or sofosbuvir with daclatasvir (8). Individuals who have had prior DAA therapy and require additional treatment are recommended to be treated with sofosbuvir, velpatasvir, and voxilaprevir (9).

The early stages of infection with HCV are usually asymptomatic—between 15-45% of people spontaneously clear the virus within 6 months of infection without any treatment. The remaining 55–85% of people will develop chronic HCV infection, which may also be asymptomatic for many years (10). However, during the natural course of HCV infection, individuals develop liver fibrosis, which, without treatment, can progress to liver cirrhosis and liver cancer (hepatocellular carcinoma). The risk of developing liver cancer for an individual with HCV-related cirrhosis is approximately 2-6% per year (11).

HCV is classified by genotype, based on the nucleotide sequence of the viral RNA. There are 6 major classes of genotype, numbered 1–6, with multiple subtypes such as 1a, 1b, 2a, 2b. In the US, approximately 70% of people with HCV infection have genotype 1, with genotype 1a more common than 1b (10). Genotype 1 was formerly the most difficult to cure with interferon-based therapies, as it was less likely than genotypes 2 and 3 to respond to therapy. With the introduction of DAA-based treatments, this is no longer the case.

Sofosbuvir is indicated for the treatment of genotype 1, 2, 3 or 4 chronic HCV infection and is generally considered to have moderate to high efficacy for all 6 genotypes (12). For the treatment of genotype 1 or 4 infections, the drug label recommends a combination therapy of sofosbuvir plus peginterferon alfa and ribavirin. For the treatment of genotype 2 or 3 infections, the combination therapy of sofosbuvir plus ribavirin is recommended (1).

Sofosbuvir is an NS5B nucleotide analogue and a prodrug. Once inside a liver cell, sofosbuvir is metabolized through multiple steps to form a nucleoside triphosphate that competes with nucleotides during viral replication but does not interfere with host transcription. Following absorption, sofosbuvir is hydrolyzed by cathepsin A (encoded by CTSA on chromosome 20q13.12) and carboxylesterase 1 (encoded by CES1 on chromosome 16q12.2), then cleaved by histidine triad nucleotide-binding protein 1 (HINT1, encoded by the HINT1 gene), and phosphorylated by nucleoside diphosphate (NDP) kinase (encoded by NME1) (13). The result is the pharmacologically active uridine analog 5’-triphosphate (GS-461203) (1, 14, 15). Binding of this analog to the viral NS5B polymerase results in RNA chain termination, thus inhibiting the virus from replicating its genome (16).

The safety and efficacy of sofosbuvir has been established in several clinical trials. The usual dose of sofosbuvir is a 400mg tablet, taken once a day for 12 weeks with other antiviral agents. Sofosbuvir is generally well tolerated, with no adverse effects beyond those associated with placebo therapy in individuals who are hepatitis B negative (12, 17). However, there is a risk of hepatitis B reactivation in co-infected individuals, which can result in fulminant hepatitis, hepatic failure and death (1). The duration of treatment may be extended for certain regimens in individuals with compensated cirrhosis or specific HCV genotype (1, 8).

The use of sofosbuvir and other DAAs in an elderly population is also approved by the US and international regulatory bodies (1, 18, 19, 20). A review of available clinical data reports that the efficacy and safety of DAAs, including sofosbuvir, were comparable in elderly (>65 years old) and non-elderly adults (20). One notable concern in this group is the higher incidence of polypharmacy and risk for drug-drug interactions. Statins and antipsychotics are drug classes that are commonly prescribed in this group, but both are contraindicated with DAAs (21). Other medications with potentially clinically significant interactions include calcium channel blockers and proton pump inhibitors (21).

Sofosbuvir is approved by the FDA for use in a pediatric population (aged 3 or older) for genotype 2 or 3 HCV (1). The recommended combination therapy is sofosbuvir and ribavirin for 12 weeks to treat genotype 2 and 24 weeks to treat genotype 3, with dosing calculated based on body weight (1). A combination of sofosbuvir and ledipasvir is also approved by the FDA and European Medicines Agency for pediatric treatment of genotypes 1, 4, 5 or 6 HCV infection (22). Additional approved combination therapies that have pangenotypic activity include sofosbuvir and velpatasvir (marketed under the brand name Epclusa) and sofosbuvir, velpatasivr, and voxilaprevir (7, 22, 23). Sofosbuvir is not authorized for pediatric use in Canada (18).

Vertical transmission from mother to child is the most common mode of pediatric HCV infection. However, data and recommendations are lacking regarding the safety of DAA therapy during pregnancy, including for sofosbuvir (1). Animal studies showed no evidence of adverse developmental outcomes with sofosbuvir exposure, though there are no well controlled clinical studies in humans, putting this and many other DAA medications in the pregnancy class B category (1, 24). The American College of Obstetricians and Gynecologists (ACOG) recommends that women should be screened for hepatitis C antibodies in each pregnancy; ACOG also recommends pre-pregnancy screening for HCV infection and treatment (when possible) before becoming pregnant (25). Women with HCV infection are at increased risk of fetal growth restriction, preterm birth, and intrahepatic cholestasis of pregnancy (25). Ribavirin therapy in either the male or female should be completed 6 months before planned conception due to teratogenic effects of ribavirin (1, 25). One observational study from India reported on findings in 26 pregnant women treated with sofosbuvir and ledipasvir and none of the infants born to these mothers were found to have congenital malformations nor detectable HCV RNA at 6 months of age (26).

Breastfeeding is not contraindicated for mothers with HCV infection, given the overall body of evidence does not suggest a risk of mother to child transmission via breastmilk (5). However, use of sofosbuvir in nursing mothers is not well studied. Use of sofosbuvir, alone or with ledipasvir, is not a reason to discontinue breastfeeding (27). If the mother experiences cracked or bleeding nipples, it is recommended to stop breastfeeding since HCV is a blood-borne infection (27).

Genetic variants in the IFNL4 gene have been shown to strongly influence treatment response to peginterferon-based regimens in previously untreated individuals with HCV genotype 1 infection (5, 28). Such variants also appear to influence the outcomes of treatment regimens that include sofosbuvir. For example, the rs12979860 genotype predicts the response to 8 weeks of treatment with sofosbuvir/ledipasvir (29).

In addition, several substitutions that occur within the viral NS5B polymerase have been reported. Most notably, an S282T polymorphism has been associated with sofosbuvir resistance (30). In cell cultures, the S282T substitution is associated with a reduced susceptibility to sofosbuvir. However, the clinical significance of such substitutions is not yet known, as they appear to be detrimental to viral fitness. So far, the S282T substitution has only been detected in one individual who experienced a relapse while being treated with sofosbuvir monotherapy in a trial, and the substitution was not detected at week 12 post-treatment (1).

## Gene: IFNL4

The IFNL4 gene (located on chromosome 19q13.2) encodes interferon lambda-4 (IFN-λ4) and is involved in the immune response to hepatitis C. There are 3 classes of IFNs: type I (IFN-α/β), type II (IFN-γ), and type III (IFN-λ). The most recent interferon to be discovered, IFNL4, belongs to the type III class (31). It is located upstream of IFNL3 (also located on chromosome 19q13.2) and is a functional gene in the majority (>95%) of the African population. But in roughly 50% of the European population and in most of the east Asian population, IFNL4 is a pseudogene, created by a frameshift polymorphism (once identified as rs368234815, it has been more recently mapped to rs11322783) (32, 33, 34). The ancestral allele is the ΔG (also written as delG) variant, which encodes a functional protein. The ΔG allele is present in approximately 95% of African ancestry individuals and less than 15% of Asian ancestry populations (31). The TT allele introduces a frameshift and premature termination codon or, in some cell lines, produces inactive proteins (31, 32, 35).

When a person is infected by viruses, including HCV, their immune response includes the production of interferons. These signaling proteins induce changes in infected and uninfected cells to block the viral replication cycle and stop the spread of virus. Interferons may be given as part of treatment for HCV to strengthen this innate response.

As a type III interferon, IFNL4 induces an antiviral state in responsive cells with a higher risk of viral infection, such as mucosal cells (33). IFNL4 exerts its actions by interacting with a cytokine receptor complex, which is composed of the IL10RB and IFNLR1 receptor chains (5). Expression of IFNLR1 is largely restricted to cells of epithelial origin, which includes hepatocytes. In contrast, receptors for type I interferons, such as IFN-α, are expressed in most cell types. Upon binding to their receptors, type I and type III IFNs activate protein kinase signaling cascades like Jak-STAT and MAPK pathways which lead to changes in gene expression. In most cases, this leads to an anti-viral cellular response. Paradoxically, however, in humans reduced IFNL4 function corresponds to improved HCV clearance, either spontaneously or in response to antiviral therapy (31).

The 2 IFNL4 variants that have been most frequently tested are rs12979860 (located in IFNL4) and rs8099917, which lies proximate to IFNL4. These variants are in strong linkage disequilibrium and are commonly inherited together, though the degree of linkage varies across ancestral populations (5, 31). These alleles are also in linkage disequilibrium with rs11322783, particularly the context of European ancestry (36). The frequency of the rs12979860 ‘C’ allele varies globally across different populations—it is commonly found in East Asians (allele frequency nearly 0.9), followed by Caucasians (0.63) and Hispanics (0.55), and is the least common among individuals of African origin (0.39) (Table 1) (5). Variation at the IFNL4 locus has also been studied as a potential factor in clinical malaria episodes, COVID-19 infection and recovery, HBV, as well as other pediatric infections (37, 38, 39, 40, 41).

Other genes of note:

Carboxylesterase 1 (encoded by CES1) is a key enzyme in metabolism of sofosbuvir to generate the active antiviral compound. It is also associated with capecitabine toxicity, dabigatran plasma levels, and clopidogrel response due to its role in metabolism of these drugs (42). Variation in CES1 associated with reduced enzymatic activity was enriched in individuals who failed sofosbuvir-based HCV regimens. The odds ratio of treatment failure for CES1 variants and reduced function was 5.43 (P=0.0057) in the European ancestry subset of the study population (42). In the context of the full study population, the odds ratio was 2.86 and P=0.058, highlighting the CES1 locus as a strong candidate for future studies (42).

An additional association has also been noted for IL10RB and treatment response to sofosbuvir. The IL10RB locus encodes an IFNL4 receptor and a variant (rs2834167, p.Lys47Glu) that has been shown to increase expression as well as downstream IFNL4-based signaling was associated with treatment failure (odds ratio 1.81, P=0.047). (42).

Forkhead box P3 transcription factor (encoded by FOXP3 on chromosome Xp11.23) is associated with regulatory T cell activation and immunosuppression following persistent antigen exposure. The FOXP3 rs2232365 A to G polymorphism was found to be significantly associated with increased risk of non-response to DAA for an Egyptian cohort being treated for HCV (43). The variant correlated with higher levels of FOXP3 protein in serum and was associated with poor response to a standard sofosbuvir-containing DAA regimen.

## Genetic Testing

The US FDA has information regarding approved tests for hepatitis C (https://www.fda.gov/vaccines-blood-biologics/hepatitis-c) and hepatitis B (https://www.fda.gov/vaccines-blood-biologics/hepatitis-b) to determine HCV genotype and HBV co-infection status before initiating therapy with sofosbuvir. The NIH Genetic Testing Registry (GTR) includes tests for IFNL4 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=IFNL4). Genetic testing for IFNL4 is used to predict response to peginterferon and ribavirin in HCV genotype 1 positive individuals. The results can help clinicians and individuals make informed decisions on how to manage HCV infection.

The rs12979860 variant is most commonly tested, and the results are typically reported in the following format (5):

- rs12979860 C/C, favorable genotype
- rs12979860 C/T, unfavorable genotype
- rs12979860 T/T, unfavorable genotype

Other studies suggest that individuals with the non-functional rs11322783 TT IFNL4 genotype may achieve SVR following an 8-week course of sofosbuvir-based DAAs, rather than the standard 12-week course (36). A point-of-care rapid genotyping test for rs12979860 C>T variation has been developed to help identify non-CC genotype individuals who may not be good candidates for interferon-based therapy (44).

## Linking IFNL4 Genetic Variation with Treatment Response

Rates of DAA failure for HCV have been reported to range from 4.4% to 9.5% (36, 42). Factors such as HCV genotype as well as the individual’s age, biological sex, and ancestral background have been examined to try and identify the major components that predict treatment failure or success. Additionally, individual genetic variants have been identified at multiple loci that associate with higher or lower rates of SVR in response to sofosbuvir or other DAA regimens. The data from the literature indicate that higher levels of IFNL4 expression or activity correlate with reduced sofosbuvir treatment response and lower spontaneous clearance rate for HCV infection of multiple viral genotypes. Thus, populations that have a higher frequency of the functional IFNL4 allele (such as individuals with African ancestry) are less likely to respond to DAA. The clinical impact on antiviral treatment response and approximate allele frequencies for IFNL4 alleles is summarized in Table 1 and described in more detail below.

Table 1.

Notable IFNL4 Alleles and approximate population frequencies

Allele ID | Variation | Clinical impact | Population Allele Frequencies (ALFA)
Allele ID | Variation | Clinical impact | African^1^ | African American | Asian | European | Latin American^1^
rs12979860 | C>T | C: more responsive to treatment | C= 0.38 T=0.62 | C= 0.43 T=0.57 | C=0.96 T=0.04 | C= 0.69 T= 0.31 | C=0.63 T=0.37
rs8099917 | T>G (Coding A>C) | T/T: more responsive to treatment | T= 0.95 G=0.05 | T= 0.93 G= 0.07 | T= 0.95 G= 0.05 | T= 0.80 G= 0.20 | T= 0.75 G= 0.25
rs11322783 | TT >T or delTTinsG (ΔG) | TT: more responsive to treatment | TT=0.34 T=0.66 | TT= 0.38 T=0.62 | TT=0.94 T=0.06 | TT=0.62 T=0.38 | TT=0.64 T=0.36
rs117648444 | G>A | A: more responsive to treatment | G=0.95 A=0.05 | G=0.93 A=0.07 | G=1.0 A=0.0 | G=0.90 A=0.10 | G=0.96 A=0.04

^1^ This allele frequency represents the average between 2 reported populations in ALFA for this geographic region.

Allele frequencies are from the Allele Frequency Aggregator (ALFA) project (45). Clinical impact regarding response to antiviral therapy is based on various reports cited throughout the text.

HCV genotype 1 infected individuals with the “favorable” genotypes (CC for rs12979860 and TT for rs8099917) respond better to interferon-based treatment—favorable genotypes are associated with a 2 to 3 fold increase in SVR (5, 46, 47, 48, 49). However, for specific treatment regimens which include sofosbuvir, although an individual’s IFNL4 genotype still influences treatment outcomes, the SVR for non-favorable genotype remains relatively high at 71—75% (1).

In the NEUTRINO study, individuals with HCV genotype 1 or 4 who had not received previous treatments for HCV infection were treated with a regimen of sofosbuvir plus peginterferon and ribavirin for 12 weeks. The SVR12 rate was 99% (89/90) in subjects with rs12979860 C/C alleles and 87% (200/230) in subjects with rs12979860 non-C/C alleles (6). A study of genotype 4 HCV infected individuals treated with sofosbuvir and daclatasvir also studied the effect of genetic variation at rs12979860. Individuals with the CC genotype had significantly higher rates of rapid virologic response than all other genotypes; only non-CC genotype individuals relapsed or failed to respond to the DAA therapy (50). The benefit of CC genotype at this site was also observed in individuals with genotype 2 or 3 HCV, with 82% of individuals achieving SVR following peginterferon and ribavirin therapy, as compared with 75% of individuals with CT genotype and 58% of TT genotype individuals (51).

Similarly, in the PHOTON trial, individuals with HCV genotype 1 infection and co-infection with HIV were treated with a combination of sofosbuvir and ribavarin. The SVR12 rates were 80% (24/30) in subjects with rs12979860 C/C allele and 75% (62/83) in subjects with rs12979860 non-C/C alleles (1). Analysis of data from the ION-3 trial subgroups found that individuals with rs12979860-C/C genotype had an SVR rate of 98.2% (29), notably higher than the 93–95% overall SVR for the different treatment groups from each trial arm (52). A smaller retrospective cohort study observed an enrichment for rs12979860 C/C genotype in chronic HCV responders versus non-responders following 12 weeks of sofosbuvir-containing DAA (49). A similar trend was observed by Khan et al. in their 250-person study which enrolled individuals with genotype 3 HCV; the T/T genotype at rs12979860 was observed more often in individuals with chronic infection and those who failed to achieve SVR (53). Individuals with chronic genotype 4 HCV infection with CC genotype at rs12979860 were approximately 2 times more sensitive to a sofosbuvir/DAC combination therapy and the TT genotype individuals were enriched in the non-responder group compared with the responder group (57.1% of non-responders versus 42.9% of responders) (43).

Variation at rs8099917 (T/T genotype) is also associated with reduced viral load in chronic HCV (54) as well as higher rates of spontaneous HCV clearance (43, 55). The G/G genotype at rs8099917 has been associated with higher rates of treatment failure or relapse, whereas the T/T genotype was associated with higher likelihood of SVR (53). In the context of sofosbuvir-based DAA therapy, one study in an Egyptian cohort observed no association between genotype at rs8099917 and treatment response (43).

Individuals who have the IFNL4 expressing variant (rs11322783 delG) are more likely to fail DAA regimens with sofosbuvir as compared with individuals that have the homozygous T/T allele genotype (32, 36, 56). In many cases, the rs12979860 genotype is used as a proxy for rs11322783 genotyping, but this is not always reliable. In individuals of African ancestry, the rs11322783 (previously identified as rs368234815) variant is superior to rs12979860 in predicting treatment outcomes; together with another IFNL4 variant (rs117648444), the combination of testing these 2 variants gives a superior treatment response prediction compared to testing for single variants (32, 33). A third site, rs8109886, has also been identified as a potential predictive marker for SVR when an individual has the C/C genotype; though combination of multiple variant genotype calls had a stronger impact on the prediction of SVR in the context of pegylated-interferon alpha based therapy (46).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

Statement from the US Food and Drug Administration (FDA): NEUTRINO was an open-label, single-arm trial that evaluated 12 weeks of treatment with sofosbuvir in combination with peginterferon alfa 2a and ribavirin in treatment-naïve subjects with genotype 1, 4, 5 or 6 HCV infection compared to pre-specified historical control. [...] SVR12 rates were 99% (89/90) in subjects with genotype 1 or 4 HCV and baseline IL28B C/C allele and 87% (200/230) in subjects with genotype 1 or 4 HCV and baseline IL28B non-C/C alleles^2^.

It is estimated that the SVR12 in individuals who previously failed pegylated interferon and ribavirin therapy will approximate the observed SVR12 in NEUTRINO subjects with multiple baseline factors traditionally associated with a lower response to interferon-based treatment. The SVR12 rate in the NEUTRINO trial in genotype 1 subjects with IL28B non-C/C alleles, HCV RNA greater than 800,000 IU/mL and Metavir F3/F4 fibrosis was 71% (37/52).

[…]

In a pooled analysis of 982 subjects who received sofosbuvir in Phase 3 trials, 224 subjects had post- baseline NS5B genotypic data from next generation nucleotide sequencing (assay cutoff of 1%).

Treatment-emergent substitutions L159F (n=6) and V321A (n=5) were detected in post-baseline samples from GT3a-infected subjects across the Phase 3 trials. No detectable shift in the phenotypic susceptibility to sofosbuvir of subject isolates with L159F or V321A substitutions was seen. The sofosbuvir-associated resistance substitution S282T was not detected at baseline or in the failure isolates from Phase 3 trials. However, an S282T substitution was detected in one genotype 2b subject who relapsed at Week 4 post-treatment after 12 weeks of sofosbuvir monotherapy in the Phase 2 trial P7977-0523 [ELECTRON]. The isolate from this subject displayed a mean 13.5-fold reduced susceptibility to sofosbuvir. For this subject, the S282T substitution was no longer detectable at Week 12 post-treatment by next generation sequencing with an assay cutoff of 1%.

Please review the complete therapeutic recommendations that are located here: (1).

## Nomenclature for Select IFNL4 Variants

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
rs12979860 | -- | NM_001276254.2:c.151-152G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/225949/) | N/A | rs12979860 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=12979860)
rs8099917 | -- | NG_055295.1:g.1332A>C | N/A | rs8099917 (https://www.ncbi.nlm.nih.gov/snp/rs8099917)
rs11322783 | rs368234815 TT | NM_001276254.2:c.65delinsAA | NP_001263183.2:p.Ala22fs | rs11322783 (https://www.ncbi.nlm.nih.gov/snp/rs11322783)
rs11322783 | rs368234815 delG | NM_001276254.2:c.65= | NP_001263183.2:p.Ala22= | rs11322783 (https://www.ncbi.nlm.nih.gov/snp/rs11322783)
rs117648444 | -- | NM_001276254.2:c.208C>T | NP_001263183.2:p.Pro70Ser | rs117648444 (https://www.ncbi.nlm.nih.gov/snp/rs117648444)

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (57).

## Acknowledgments

Version 2.0 (Published May 22, 2025) The author would like to thank Bruce C. Carleton, B.Pharm, Pharm.D, FCP, FISPE, Professor and Chair, Division of Translational Therapeutics, University of British Colombia and BC Children’s Hospital and Research Institute Vancouver, BC; Catrina M. Loucks, BHSc, MSc, PhD, Assistant Professor, Division of Translational Therapeutics, Department of Pediatrics, and Department of Anesthesiology, Pharmacology & Therapeutics, University of British Columbia and BC Children's Hospital Research Institute, Vancouver, BC, Canada; and Wafaa M. Rashed, MSc, PhD, Lecturer, Chair & Founder of Pan-African PGS Education and Research Initiative and MicroRNA Childhood Cancer Catalog, Faculty of Pharmacy, Ahram Canadian University, 6^th^ of October City, Egypt, for reviewing this summary.

Version 1.0 (Published January 25, 2017): The author would like to thank Teresa Beam, Ph.D., Chair, Department of Pharmaceutical Sciences, Manchester University, Indiana; David Kisor, B.S., Pharm.D., Professor and Director of Pharmacogenomics Education, Pharmacogenomics Program, Manchester University, Indiana; Martin Lagging, MD, PhD, Professor, Department of Infectious Medicine / Virology, Institute of Biomedicine, Sahlgrenska Academy, University of Gothenburg, Sweden; and Thomas R. O’Brien, M.D., M.P.H., Senior Investigator, National Cancer Institute, Division of Cancer Epidemiology & Genetics, Infections and Immunoepidemiology Branch; for reviewing this summary.

## Version History

Version 2.0 was published on May, 22 2025. This version includes a review of additional literature and studies completed since the 2017 Version 1.0 was published. There is no change in regulatory or professional society guidance for genotype-based prescribing of sofosbuvir since the prior version of this chapter.

Version 1.0 was published on January 25, 2017 and is available here.

## References

1 SOVALDI- sofosbuvir tablet, film coated. Foster City, CA, USA: Gilead Sciences Inc.; 2023. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=80beab2c-396e-4a37-a4dc-40fdb62859cf.
2 Messina, J.P., I. Humphreys, A. Flaxman, A. Brown, et al., Global distribution and prevalence of hepatitis C virus genotypes. Hepatology, 2015. 61(1): p. 77-87.25069599
3 Panel, A.I.H.G., Hepatitis C guidance: AASLD-IDSA recommendations for testing, managing, and treating adults infected with hepatitis C virus. Hepatology, 2015. 62(3): p. 932-54.26111063
4 Nakayama, M., H. Kobayashi, K. Fukushima, M. Ishido, et al., Predictive factors for 24 weeks sustained virologic response (SVR24) and viral relapse in patients treated with simeprevir plus peginterferon and ribavirin. Hepatol Int, 2016. 10(1): p. 158-68.26264253
5 Muir, A.J., L. Gong, S.G. Johnson, M.T. Lee, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) guidelines for IFNL3 (IL28B) genotype and PEG interferon-alpha-based regimens. Clin Pharmacol Ther, 2014. 95(2): p. 141-6.24096968
6 Lawitz, E., A. Mangia, D. Wyles, M. Rodriguez-Torres, et al., Sofosbuvir for previously untreated chronic hepatitis C infection. N Engl J Med, 2013. 368(20): p. 1878-87.23607594
7 Jarasvaraparn, C., C. Hartley, and W. Karnsakul, Updated Clinical Guidelines on the Management of Hepatitis C Infection in Children. Pathogens, 2024. 13(2).38392918
8 New recommendation on hepatitis C virus testing and treatment for people at ongoing risk of infection: policy brief. [Cited 7 November 2024]. Available from https://iris.who.int/handle/10665/366869.
9 Liu, C.H., Y.P. Chang, and J.H. Kao, Cutting-edge pharmacotherapy for hepatitis C virus infection: a comprehensive review. Expert Opin Pharmacother, 2024. 25(12): p. 1691-1706.39169665
10 Muir, A.J., The rapid evolution of treatment strategies for hepatitis C. Am J Gastroenterol, 2014. 109(5): p. 628-35; quiz 636.24732866
11 Sangiovanni, A., E. Del Ninno, P. Fasani, C. De Fazio, et al., Increased survival of cirrhotic patients with a hepatocellular carcinoma detected during surveillance. Gastroenterology, 2004. 126(4): p. 1005-14.15057740
12 Welzel, T.M., D.R. Nelson, G. Morelli, A. Di Bisceglie, et al., Effectiveness and safety of sofosbuvir plus ribavirin for the treatment of HCV genotype 2 infection: results of the real-world, clinical practice HCV-TARGET study. Gut, 2016.27418632
13 Ibrahim, M.K., M. AbdElrahman, N.G. Bader El Din, S. Tawfik, et al., The impact of genetic variations in sofosbuvir metabolizing enzymes and innate immunity mediators on treatment outcome in HCV-infected patients. Microb Pathog, 2022. 162: p. 105311.34843922
14 Whirl-Carrillo, M., R. Huddart, L. Gong, K. Sangkuhl, et al., An Evidence-Based Framework for Evaluating Pharmacogenomics Knowledge for Personalized Medicine. Clin Pharmacol Ther, 2021. 110(3): p. 563-572.34216021
15 Thorn, C.F. In Progress: Sofosbuvir Pathway, Pharmacokinetics. 2022 16 April 2025]; Available from: https://www.pharmgkb.org/pathway/PA166264501.
16 Bhatia, H.K., H. Singh, N. Grewal, and N.K. Natt, Sofosbuvir: A novel treatment option for chronic hepatitis C infection. J Pharmacol Pharmacother, 2014. 5(4): p. 278-84.25422576
17 Cortez, K.J. and S. Kottilil, Beyond interferon: rationale and prospects for newer treatment paradigms for chronic hepatitis C. Ther Adv Chronic Dis, 2015. 6(1): p. 4-14.25553238
18 PRODUCT MONOGRAPH INCLUDING PATIENT MEDICATION INFORMATION, SOVALDI. Mississauga, ON, Canada: Gilead Sciences Canada Inc.; 2021. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=90293.
19 Sovaldi : EPAR - Product Information. Carrigtohill, County Cork, Ireland: Gilead Sciences Ireland UC; 2022. Available from: https://www.ema.europa.eu/en/documents/product-information/sovaldi-epar-product-information_en.pdf.
20 Pugliese, N., D. Polverini, I. Arcari, S. De Nicola, et al., Hepatitis C Virus Infection in the Elderly in the Era of Direct-Acting Antivirals: Evidence from Clinical Trials and Real Life. Trop Med Infect Dis, 2023. 8(11).37999621
21 Hui, V.W., C.L. Au, A.S.M. Lam, T.C. Yip, et al., Drug-drug interactions between direct-acting antivirals and co-medications: a territory-wide cohort study. Hepatol Int, 2022. 16(6): p. 1318-1329.36074319
22 Indolfi, G., R.P. Gonzalez-Peralta, M.M. Jonas, M.H. Sayed, et al., ESPGHAN recommendations on treatment of chronic hepatitis C virus infection in adolescents and children including those living in resource-limited settings. J Pediatr Gastroenterol Nutr, 2024. 78(4): p. 957-972.38369891
23 EPCLUSA- velpatasvir and sofosbuvir tablet, film coated. Foster City, CA, USA: Gilead Sciences Inc.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=7f30631a-ee3b-4cfe-866b-964df3f0a44f.
24 Hartley, C., T. Van, and W. Karnsakul, Direct-Acting Antiviral Agents in Prevention of Maternal-Fetal Transmission of Hepatitis C Virus in Pregnancy. Pathogens, 2024. 13(6).38921805
25 Viral Hepatitis in Pregnancy: ACOG Clinical Practice Guideline No. 6. Obstet Gynecol, 2023. 142(3): p. 745-759.37590986
26 Yattoo, G.N., S.M. Shafi, G.A. Dar, J.S. Sodhi, et al., Safety and efficacy of treatment for chronic hepatitis C during pregnancy: A prospective observational study in Srinagar, India. Clin Liver Dis (Hoboken), 2023. 22(4): p. 134-139.37908870
27 Sofosbuvir, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/29999883.
28 Rembeck, K. and M. Lagging, Impact of IL28B, ITPA and PNPLA3 genetic variants on therapeutic outcome and progression of hepatitis C virus infection. Pharmacogenomics, 2015. 16(10): p. 1179-88.26250055
29 O'Brien, T.R., K.A. Lang Kuhs, and R.M. Pfeiffer, Subgroup differences in response to 8 weeks of ledipasvir/sofosbuvir for chronic hepatitis C. Open Forum Infect Dis, 2014. 1(3): p. ofu110.25734178
30 Hedskog, C., H. Dvory-Sobol, V. Gontcharova, R. Martin, et al., Evolution of the HCV viral population from a patient with S282T detected at relapse after sofosbuvir monotherapy. J Viral Hepat, 2015. 22(11): p. 871-81.25784085
31 Fang, M.Z., S.S. Jackson, and T.R. O'Brien, IFNL4: Notable variants and associated phenotypes(). Gene, 2020. 730: p. 144289.31846709
32 Prokunina-Olsson, L., B. Muchmore, W. Tang, R.M. Pfeiffer, et al., A variant upstream of IFNL3 (IL28B) creating a new interferon gene IFNL4 is associated with impaired clearance of hepatitis C virus. Nat Genet, 2013. 45(2): p. 164-71.23291588
33 Wack, A., E. Terczynska-Dyla, and R. Hartmann, Guarding the frontiers: the biology of type III interferons. Nat Immunol, 2015. 16(8): p. 802-9.26194286
34 Chinnaswamy, S., Gene-disease association with human IFNL locus polymorphisms extends beyond hepatitis C virus infections. Genes Immun, 2016. 17(5): p. 265-75.27278127
35 Bharatiya, S., A. Agarwal, and S. Chinnaswamy, A Novel Inactive Isoform with a Restored Reading Frame Is Expressed from the Human Interferon Lambda 4 TT Allele at rs368234815. J Interferon Cytokine Res, 2023. 43(9): p. 370-378.36880961
36 O'Brien, T.R., D.J. Witt, V. Saxena, K.G. Morrissey, et al., IFNL4 genotype and other personal characteristics to predict response to 8-week sofosbuvir-based treatment for chronic hepatitis C. J Infect, 2024. 89(5): p. 106258.39216831
37 Samayoa-Reyes, G., C. Jackson, S. Ogolla, K. Sabourin, et al., IFN-lambda4 genetic variants influence clinical malaria episodes in a cohort of Kenyan children. Malar J, 2021. 20(1): p. 196.33882912
38 Sorrentino, L., V. Silvestri, G. Oliveto, M. Scordio, et al., Distribution of Interferon Lambda 4 Single Nucleotide Polymorphism rs11322783 Genotypes in Patients with COVID-19. Microorganisms, 2022. 10(2).35208821
39 Rahimi, P., R. Tarharoudi, A. Rahimpour, J. Mosayebi Amroabadi, et al., The association between interferon lambda 3 and 4 gene single-nucleotide polymorphisms and the recovery of COVID-19 patients. Virol J, 2021. 18(1): p. 221.34775984
40 Chihab, H., W. Badre, M. Tahiri, F.Z. Jadid, et al., IFNL4 rs12979860 polymorphism influences HBV DNA viral loads but not the outcome of HBV infection in Moroccan patients. Microbes Infect, 2021. 23(4-5): p. 104802.33607264
41 Prokunina-Olsson, L., R.D. Morrison, A. Obajemu, A. Mahamar, et al., IFN-lambda4 is associated with increased risk and earlier occurrence of several common infections in African children. Genes Immun, 2021. 22(1): p. 44-55.33850301
42 Loucks, C.M., J.J. Lin, J.N. Trueman, B.I. Drogemoller, et al., Patient-specific genetic factors predict treatment failure in sofosbuvir-treated patients with chronic hepatitis C. Liver Int, 2022. 42(4): p. 796-808.35107877
43 Abdelaziz, A.I., E. Abdelsameea, M. Abdel-Samiee, S.E. Ghanem, et al., Effect of immunogenetics polymorphism and expression on direct-acting antiviral drug response in chronic hepatitis C. Clin Exp Med, 2024. 24(1): p. 184.39117877
44 Sy, A., L. McCabe, E. Hudson, A.M. Ansari, et al., Utility of a buccal swab point-of-care test for the IFNL4 genotype in the era of direct acting antivirals for hepatitis C virus. PLoS One, 2023. 18(1): p. e0280551.36689413
45 ALFA: Allele Frequency Aggregator [Cited 16 April 2025]. Available from www.ncbi.nlm.nih.gov/snp/docs/gsr/alfa/ (https://nih-my.sharepoint.com/personal/kanems_nih_gov/Documents/MGS%20Files/On-going%20Summaries/Sofosbuvir_2024Update/www.ncbi.nlm.nih.gov/snp/docs/gsr/alfa/).
46 da Silva, A.M.V., L.E. Alvarado-Arnez, T. Azamor, L.R. Batista-Silva, et al., Interferon-lambda 3 and 4 Polymorphisms Increase Sustained Virological Responses and Regulate Innate Immunity in Antiviral Therapy With Pegylated Interferon-Alpha. Front Cell Infect Microbiol, 2021. 11: p. 656393.34307188
47 Ge, D., J. Fellay, A.J. Thompson, J.S. Simon, et al., Genetic variation in IL28B predicts hepatitis C treatment-induced viral clearance. Nature, 2009. 461(7262): p. 399-401.19684573
48 Ciesla, A., M. Bociaga-Jasik, I. Sobczyk-Krupiarz, M.K. Glowacki, et al., IL28B polymorphism as a predictor of antiviral response in chronic hepatitis C. World J Gastroenterol, 2012. 18(35): p. 4892-7.23002361
49 Zaki, S.M., H.S. Ahmed, M.M. Yousif, and E.M. Awad, Interleukin 28B Polymorphism as a Predictor of Sustained Virological Response to Sofosbuvir-Based Therapy for Hepatitis C Virus Patients. Trop Med Infect Dis, 2022. 7(9).36136642
50 Hassanien, K.S., E.M. El-Sayed, R.S. Ismail, Z.M. Zakarya, and G.K. Helal, Association between interleukin 28B polymorphism and sustained virological response to sofosbuvir plus daclatasvir in chronic hepatitis C genotype 4 Egyptian patients. J Clin Pharm Ther, 2021. 46(4): p. 942-949.33768560
51 Mangia, A., A.J. Thompson, R. Santoro, V. Piazzolla, et al., An IL28B polymorphism determines treatment response of hepatitis C virus genotype 2 or 3 patients who do not achieve a rapid virologic response. Gastroenterology, 2010. 139(3): p. 821-7, 827 e1.
52 Kowdley, K.V., S.C. Gordon, K.R. Reddy, L. Rossaro, et al., Ledipasvir and sofosbuvir for 8 or 12 weeks for chronic HCV without cirrhosis. N Engl J Med, 2014. 370(20): p. 1879-88.24720702
53 Khan, A.J., V.A. Saraswat, P. Ranjan, D. Parmar, et al., Polymorphism in interferon lambda3/interleukin-28B gene and risk to noncirrhotic chronic hepatitis C genotype 3 virus infection and its effect on the response to combined daclatasvir and sofosbuvir therapy. J Med Virol, 2019. 91(4): p. 659-667.30431653
54 Zakaria, Z.A., S. Knapp, M. Hashem, H. Zaghla, et al., Interleukin 28A.rs12980602 and interleukin 28B.rs8103142 genotypes could be protective against HCV infection among Egyptians. Immunol Res, 2019. 67(1): p. 123-133.30402710
55 Sardar, S., S. Muhammad, M. Haq, N.U. Haq, and A.M. Kashif Khan, Predictive Potential Of Il28b Gene In Hcv Patients, Resistant To Daclatasvir And Sofosbuvir In KPK Population. J Ayub Med Coll Abbottabad, 2023. 35(4): p. 523-529.38406928
56 O'Brien, T.R., S. Kottilil, and R.M. Pfeiffer, IFNL4 Genotype Is Associated With Virologic Relapse After 8-Week Treatment With Sofosbuvir, Velpatasvir, and Voxilaprevir. Gastroenterology, 2017. 153(6): p. 1694-1695.29107709
57 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564-9.26931183

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

^2^ Note: Recent studies report that the rs12979860 variant is in the IFNL4 gene, and not the IFNL3 gene (previously called IL28B). Therefore, a more accurate term for describing an individual’s genotype would be “rs12979860 C/C”, instead of “IL28B C/C”.

## Tests in GTR by Gene

IFNL4 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=101180976[geneid])