# Medical Genetics Summaries Expert Reviewers

Allegra, Carmen J., MD; University of Florida Health, Gainesville, FL, USA

- Cetuximab Therapy and RAS and BRAF Genotype

Alzghari, Saeed, MS, MBA, PharmD; Gulfstream Genomics, Dallas, TX, USA

- Carbamazepine Therapy and HLA Genotype
- Carvedilol Therapy and CYP2D6 Genotype
- Warfarin Therapy and VKORC1 and CYP Genotype

Amstutz, Ursula, PhD; University of Bern, Bern, Switzerland

- Carbamazepine Therapy and HLA Genotype

Andersen, Michael Asger, MD, PhD; Copenhagen University Hospital, Copenhagen, Denmark

- Simvastatin Therapy and SLCO1B1 Genotype

Appell, Malin Lindqvist, PhD; Linköping University, Linköping, Sweden

- Thioguanine Therapy and TPMT Genotype

Badary, Osama A., PhD, MSc; The British University in Egypt, Cairo, Egypt

- Chloroquine Therapy and G6PD Genotype

Bancone, Germana, PhD; University of Oxford, Oxford, UK

- Hydroxychloroquine Therapy and G6PD Genotype

Bansal, Sumit, PhD; University of Washington, Seattle, WA, USA

- Dronabinol Therapy and CYP2C9 Genotype

Baye, Jordan, PharmD, MA, BCPS; South Dakota State University, Sioux Falls, SD, USA

- Metoprolol Therapy and CYP2D6 Genotype

Beam, Teresa, PhD; Manchester University, North Manchester, IN, USA

- Sofosbuvir Therapy and IFNL4 Genotype

Beckers, Albert, MD, PhD; University of Liège, Liège, Belgium

- McCune-Albright Syndrome

Beitelshees, Amber, PharmD, MPH, FAHA, FCCP; Baltimore, MD, USA

- Clopidogrel Therapy and CYP2C19 Genotype

Bitner-Glindzicz, Maria, PhD, FRCP; University College London, London, UK

- Gentamicin Therapy and MT-RNR1 Genotype

Bousman, Chad, MPH, PhD; University of Calgary, Calgary, AB, Canada

- Venlafaxine Therapy and CYP2D6 Genotype

Brauch, Hiltrud, PhD; Dr. Margarete Fischer-Bosch-Institute of Clinical Pharmacology (IKP), Stuttgart, Germany

- Tamoxifen Therapy and CYP2D6 Genotype

Brown, Jacob T., PharmD, MS; University of Minnesota College of Pharmacy, Duluth, MN, USA

- Atomoxetine Therapy and CYP2D6 Genotype

Burstein, Harold, MD, PhD; Harvard Medical School, Boston, MA, USA

- Tamoxifen Therapy and CYP2D6 Genotype

Callaghan, John, MD, PhD; Indiana University School of Medicine, Indianapolis, IN, USA

- Carisoprodol Therapy and CYP2C19 Genotype
- Propafenone Therapy and CYP2D6 Genotype
- Risperidone Therapy and CYP2D6 Genotype

Carleton, Bruce C., B.Pharm, Pharm.D, FCP, FISPE; University of British Colombia and BC Children’s Hospital and Research Institute Vancouver, BC, Canada

- Sofosbuvir Therapy and IFNL4 Genotype

Carpenter, William, MD; University of Maryland School of Medicine, Baltimore, MD, USA

- Clozapine Therapy and CYP2D6, CYP1A2, and CYP3A4 Genotype

Cavallari, Larisa H., PharmD; University of Florida, Gainesville, FL, USA

- Clopidogrel Therapy and CYP2C19 Genotype
- Codeine Therapy and CYP2D6 Genotype
- Metoprolol Therapy and CYP2D6 Genotype

Chapman, Paul, MD; Memorial Sloan Kettering Cancer Center, New York, NY, USA

- Vemurafenib Therapy and BRAF and NRAS Genotype

Cheon, Jae Hee, MD; Yonsei University College of Medicine, Seoul, Korea

- Thioguanine Therapy and TPMT and NUDT15 Genotype

Chung, Cecilia P., MD, MPH; Vanderbilt University Medical Center, Nashville, TN, USA

- Azathioprine Therapy and TPMT and NUDT15 Genotype

Commons, Rob, PhD, FRCAP, MPH; Ballarat Health Services, Ballarat, VIC, Menzies School of Health Research, Darwin, NT, Australia

- Tafenoquine Therapy and G6PD Genotype

Crews, Kristine, PharmD; St. Jude Children’s Research Hospital, Memphis, TN, USA

- Codeine Therapy and CYP2D6 Genotype

Cronin-Fenton, Deirdre, PhD; Aarhus University, Aarhus, Denmark

- Tamoxifen Therapy and CYP2D6 Genotype

da Silva, Izabel Cristina Rodrigues, MS, PhD; University of Brasília, Brasília, Brazil

- Venlafaxine Therapy and CYP2D6 Genotype

Daly, Adrian, MBBch, PhD; University of Liège, Liège, Belgium

- McCune-Albright Syndrome

Daud, Adil, MD; UCSF Helen Diller Family Comprehensive Cancer Center, San Francisco, CA, USA

- Vemurafenib Therapy and BRAF and NRAS Genotype

del Tredici, Andria L., PhD, Myriad Genetics, San Diego, CA, USA

- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Delate, Thomas M., PhD, MS; Kaiser Permanente National Pharmacy, University of Colorado Cancer Center, Aurora, CO, USA

- Cetuximab Therapy and RAS and BRAF Genotype

Ehret, Megan, MS, PharmD, BCPP; University of Maryland, Baltimore, MD, USA

- Aripiprazole Therapy and CYP2D6 Genotype
- Diazepam Therapy and CYP2C19 Genotype

Esquivel, Bernard, MD, MHA, PhD; Latin American Association for Personalized Medicine, Vancouver, BC, Canada

- Atomoxetine Therapy and CYP2D6 Genotype
- Azathioprine Therapy and TPMT and NUDT15 Genotype
- Carvedilol Therapy and CYP2D6 Genotype
- Diazepam Therapy and CYP2C19 Genotype
- Esomeprazole Therapy and CYP2C19 Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype
- Rasburicase Therapy and G6PD and CYB5R Genotype
- Venlafaxine Therapy and CYP2D6 Genotype
- Warfarin Therapy and VKORC1 and CYP Genotype

Eugene, Andy; MD, PhD; Shenandoah University - Fairfax Inova Center for Personalized Health, Fairfax, VA, USA

- Lesinurad Therapy and CYP2C9 Genotype

Freml, Jared, PharmD; Kaiser Permanente Colorado, University of Colorado Skaggs School of Pharmacy & Pharmaceutical Sciences, Aurora, CO, USA

- Cetuximab Therapy and RAS and BRAF Genotype

Formea, Christine, PharmD, BCPS, FCCP, FASHP; Mayo Clinic College of Medicine and Science, Rochester, MN, USA

- Warfarin Therapy and VKORC1 and CYP Genotype

Franciosi, James P., MD, MS; Nemours Children’s Hospital, University of Central Florida College of Medicine, Orlando, FL, USA

- Omeprazole Therapy and CYP2C19 Genotype

Gaedigk, Andrea, MS, PhD; University of Missouri, Kansas City, MO, USA

- Aripiprazole Therapy and CYP2D6 Genotype
- Atomoxetine Therapy and CYP2D6 Genotype
- CYP2D6 Overview: Allele and Phenotype Frequencies

Gage, Brian, MSc, MD; Washington University, St. Louis, MO, USA

- Warfarin Therapy and VKORC1 and CYP Genotype

Greenberg, Steven M., MD, PhD; Massachusetts General Hospital, Harvard Medical School, Boston, MA, USA

- Lecanemab Therapy and APOE Genotype

Grond, Stefan, MD; Klinikum Lippe, Lemgo, Germany

- Tramadol Therapy and CYP2D6 Genotype

Gupta, Anita, DO, PharmD; Drexel University College of Medicine, Philadelphia, PA, USA

- Celecoxib Therapy and CYP2C9 Genotype

Hachad, Houda, PharmD; AccessDx, Seattle, WA, USA

- Flurbiprofen Therapy and CYP2C9 Genotype
- Lesinurad Therapy and CYP2C9 Genotype
- Piroxicam Therapy and CYP2C9 Genotype
- Oxycodone Therapy and CYP2D6 Genotype
- Risperidone Therapy and CYP2D6 Genotype

Haidar, Cyrine-Eliana, PharmD, BCPS, BCOP, FASHP; St. Jude Children's Research Hospital, Memphis, TN, USA

- Chloroquine Therapy and G6PD Genotype

Hampson, Aidan, PhD; National Institutes of Health, Bethesda, MD, USA

- Oxycodone Therapy and CYP2D6 Genotype

Hardison, Matthew, PhD, FACMG; Aegis Sciences Corporation, Nashville, TN, USA

- Dabrafenib Therapy and BRAF and G6PD Genotype
- Vemurafenib Therapy and BRAF and NRAS Genotype

Henrich, Timothy, MD; Brigham and Women’s Hospital, Cambridge, MA, USA

- Maraviroc Therapy and CCR5 Genotype

Henricks, Linda, PharmD; The Netherlands Cancer Institute, Amsterdam, The Netherlands

- Capecitabine Therapy and DPYD Genotype
- Fluorouracil Therapy and DPYD Genotype

Hermosillo-Rodriguez, Jesus, MD; Colorado Permanente Medical Group, Denver, CO, USA

- Cetuximab Therapy and RAS and BRAF Genotype

Hickey, Scott, MD; Ohio State University, Columbus, OH, USA

- Methylenetetrahydrofolate Reductase Deficiency

Hiratsuka, Masahiro, PhD; Graduate School of Pharmaceutical Sciences Tohoku University, Sendai, Japan

- Fluorouracil Therapy and DPYD Genotype

Holsappel, Inge, MSc; Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands

- Abacavir Therapy and HLA-B*57:01 Genotype
- Carbamazepine Therapy and HLA Genotype
- Carvedilol Therapy and CYP2D6 Genotype
- Clopidogrel Therapy and CYP2C19 Genotype
- Esomeprazole Therapy and CYP2C19 Genotype
- Tamoxifen Therapy and CYP2D6 Genotype
- Venlafaxine Therapy and CYP2D6 Genotype
- Warfarin Therapy and VKORC1 and CYP Genotype

Hicks, David, MD; University of Rochester Medical Center, Rochester, NY, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Hudis, Clifford, MD; Weill Cornell Medical College, New York, NY, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Iwuchukwu, Otito F., RPh, PhD; Fairleigh Dickinson University School of Pharmacy, Florham Park, NJ, USA

- Irinotecan Therapy and UGT1A1 Genotype

Johnson, Douglas, MD; Vanderbilt University Medical Center, Nashville, TN, USA

- Dabrafenib Therapy and BRAF and G6PD Genotype

Jones, J. Shawn, PhD, MS; Texas Tech University Health Sciences Center, Dallas, TX, USA

- Siponimod Therapy and CYP2C9 Genotype

Jönsson, Erik, MD, PhD; Karolinska Institutet, Stockholm, Sweden

- Schizophrenia

Joshi, Avadhut, PhD; Translational Software, Bellevue, WA, USA

- Dabrafenib Therapy and BRAF and G6PD Genotype

Jukic, Marin, PhD; Karolinska Institute, Stockholm, Sweden

- Aripiprazole Therapy and CYP2D6 Genotype

Kasi, Pashtoon, MD, MS; University of Iowa Health Care, Iowa City, IA, USA

- Fluorouracil Therapy and DPYD Genotype

Karnes, Jason H., PharmD, PhD; University of Arizona College of Pharmacy and College of Medicine, Tucson, AZ, USA

- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype

Kawedia, Jitesh, PhD; University of Texas MD Anderson Cancer Center, Houston, TX, USA

- Diazepam Therapy and CYP2C19 Genotype
- Simeprevir Therapy and IFNL3 Genotype

Kaye, Alan, MD, PhD; Louisiana State University Health Sciences Center, New Orleans, LA, USA

- Tramadol Therapy and CYP2D6 Genotype

Kim, Hyun, PharmD; Boston Children’s Hospital, Boston, MA, USA

- Carbamazepine Therapy and HLA Genotype
- Gentamicin Therapy and MT-RNR1 Genotype

Kisor, David, PharmD; Manchester University, North Manchester, IN, USA

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Sofosbuvir Therapy and IFNL4 Genotype
- Thioridazine Therapy and CYP2D6 Genotype

Kong, Ben, PharmD; Oregon Health & Science University, Portland, OR, USA

- Belinostat Therapy and UGT1A1 Genotype
- Brivaracetam Therapy and CYP2C19 Genotype
- Carisoprodol Therapy and CYP2C19 Genotype
- Dabrafenib Therapy and BRAF Genotype
- Irinotecan Therapy and UGT1A1 Genotype
- Lacosamide Therapy and CYP2C19 Genotype
- Propafenone Therapy and CYP2D6 Genotype
- Risperidone Therapy and CYP2D6 Genotype
- Vemurafenib Therapy and BRAF and NRAS Genotype

Kroger, Christine, PharmD, BCACP; Allina Health Care Management, Minneapolis, MN, USA

- Siponimod Therapy and CYP2C9 Genotype

Kumar, Aditya; University of Washington, Seattle, WA, USA

- Dronabinol Therapy and CYP2C9 Genotype

Laan, Ellen T.M., PhD; Amsterdam University Medical Centre, Amsterdam, The Netherlands

- Flibanserin Therapy and CYP2C19 Genotype

Lacerda, Marcus, MD, PhD; Fundação de Medicina Tropical Dr Heitor Vieira Dourado, Instituto Leônidas & Maria Deane, Fiocruz, Manaus, Brazil

- Tafenoquine Therapy and G6PD Genotype

Lagging, Martin, MD, PhD; University of Gothenburg, Gothenburg, Sweden

- Sofosbuvir Therapy and IFNL4 Genotype

Langer, Nicolas, PhD; Child Mind Institute, New York, NY, USA

- ACHOO Syndrome

Lee, Seok-Yang, PharmD; Sungkyunkan University, Seoul, Republic of Korea

- Flurbiprofen Therapy and CYP2C9 Genotype

Leeder, Steven, PharmD, PhD; Children’s Mercy Hospital, Kansas City, MO, USA

- Aripiprazole Therapy and CYP2D6 Genotype
- Atomoxetine Therapy and CYP2D6 Genotype

Lennard, Lynne, PhD; University of Sheffield, Sheffield, UK

- Thioguanine Therapy and TPMT Genotype

de Leon, Jose, MD; University of Kentucky, KY, USA

- Clozapine Therapy and CYP Genotype

Linder, Mark, PhD; University of Louisville, Louisville, KY, USA

- Risperidone Therapy and CYP2D6 Genotype

Lipkowitz, Stanley, MD, PhD; National Cancer Institute, Bethesda, MD, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Lively, Tracy, PhD; National Cancer Institute, Bethesda, MD, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Loucks, Catrina M., BHSc, MSc, PhD; University of British Columbia and BC Children's Hospital Research Institute, Vancouver, BC, Canada

- Sofosbuvir Therapy and IFNL4 Genotype

Madi, Ayman, MD, MCRP; The Clatterbridge Cancer Centre NHS Foundation Trust, Liverpool, UK

- Fluorouracil Therapy and DPYD Genotype

Malhotra, Anil, MD; Hofstra Northwell School of Medicine, Hempstead, NY, USA

- Clozapine Therapy and CYP2D6, CYP1A2, and CYP3A4 Genotype

Mancuso, Michelangelo, MD, PhD; University of Pisa, Pisa, Italy

- Valproic Acid Therapy and POLG Genotype

Mandell, Brian F., MD, PhD, MACP, FACR; Cleveland Clinic, Cleveland Clinic Journal of Medicine, Cleveland, OH, USA

- Pegloticase Therapy and G6PD Genotype

Manzi, Shannon, PharmD, BCPPS; Boston Children’s Hospital, Boston, MA, USA

- Gentamicin Therapy and MT-RNR1 Genotype

Marinaki, Anthony, PhD; St Thomas’ Hospital, London, UK

- Thioguanine Therapy and TPMT and NUDT15 Genotype
- Mercaptopurine Therapy and TPMT and NUDT15 Genotype

McDermott, John, MRes, BSc, MBChB; University of Manchester, Manchester, UK

- Gentamicin Therapy and MT-RNR1 Genotype
- Clopidogrel Therapy and CYP2C19 Genotype

McGill, Neil William, MD; Royal Prince Alfred Hospital, Sydney, NSW, Australia

- Lesinurad Therapy and CYP2C9 Genotype

McIntyre, Roger S., MD, FRCPC; University of Toronto, Brain and Cognition Discovery Foundation (BCDF), Toronto, Ontario, Canada

- Valbenazine Therapy and CYP2D6 Genotype

Meijer, Berrie, MD, PhD; Noordwest Hospital Group, Alkmaar, The Netherlands

- Mercaptopurine Therapy and TPMT and NUDT15 Genotype

Meloche-Brouillette, Maxime, PhD; Montreal Heart Institute, Université de Montréal, Montreal, Quebec, Canada

- Metoprolol Therapy and CYP2D6 Genotype

Merl, Man Yee, PharmD, BCOP; Yale-New Haven Hospital, New Haven, CT, USA

- Irinotecan Therapy and UGT1A1 Genotype

Miller, Mark W., PhD; Boston University School of Medicine, Boston, MA, USA.

- Venlafaxine Therapy and CYP2D6 Genotype

Mistry, Pramod K., MD, PhD, FRCP, FAASLD; Yale School of Medicine, New Haven, CT

- Eliglustat Therapy and CYP2D6 Genotype

Molden, Espen, PhD; University of Oslo, Oslo, Norway

- Risperidone Therapy and CYP2D6 Genotype

Morton, Jenny, PhD, ScD; University of Cambridge, Cambridge, UK

- Deutetrabenazine Therapy and CYP2D6 Genotype

Mougey, Edward B., PhD; Nemours Children’s Specialty Care, Jacksonville, FL, USA

- Omeprazole Therapy and CYP2C19 Genotype

Mukerjee, Gouri, PhD; Geneyouin Inc., Toronto, ON, Canada

- Brivaracetam Therapy and CYP2C19 Genotype
- Carisoprodol Therapy and CYP2C19 Genotype
- Lacosamide Therapy and CYP2C19 Genotype
- Propafenone Therapy and CYP2D6 Genotype

Müller, Daniel, MD, PhD; University of Toronto, ON, Canada

- Clozapine Therapy and CYP Genotype

Murphy, Michael, MD; University of Oxford, Oxford, UK

- ABO Blood Group

Nagy, Mohamed, BPharm; Children's Cancer Hospital, Cairo, Egypt

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Capecitabine Therapy and DPYD Genotype
- Carbamazepine Therapy and HLA Genotype
- Carisoprodol Therapy and CYP2C19 Genotype
- Fluorouracil Therapy and DPYD Genotype
- Flurbiprofen Therapy and CYP2C9 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Lesinurad Therapy and CYP2C9 Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype
- Piroxicam Therapy and CYP2C9 Genotype
- Prasugrel Therapy and CYP Genotype
- Propafenone Therapy and CYP2D6 Genotype
- Risperidone Therapy and CYP2D6 Genotype
- Thioridazine Therapy and CYP2D6 Genotype

Newman, William, MA, FRCP, PhD; University of Manchester, Manchester, UK

- Gentamicin Therapy and MT-RNR1 Genotype

Nijenhuis, Marga, PhD; Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands

- Allopurinol Therapy and HLA-B*58:01 Genotype
- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Aripiprazole Therapy and CYP2D6 Genotype
- Clozapine Therapy and CYP Genotype
- Codeine Therapy and CYP2D6 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Metoprolol Therapy and CYP2D6 Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype
- Propafenone Therapy and CYP2D6 Genotype
- Simvastatin Therapy and SLCO1B1 Genotype
- Tramadol Therapy and CYP2D6 Genotype
- Venlafaxine Therapy and CYP2D6 Genotype

Nuki, George; University of Edinburgh, Edinburgh, Scotland, UK

- Pegloticase Therapy and G6PD Genotype

O’Brien, Thomas, MD, MPH; National Cancer Institute, Bethesda, MD, USA

- Sofosbuvir Therapy and IFNL4 Genotype

O’Donnell, Peter H., MD; The University of Chicago, Chicago, IL, USA

- Capecitabine Therapy and DPYD Genotype

Obeng, Aniwaa Owusu, PharmD; Icahn School of Medicine at Mount Sinai, New York, NY, USA

- Maraviroc Therapy and CCR5 Genotype
- Prasugrel Therapy and CYP Genotype

Ostrov, David A., PhD; University of Florida College of Medicine, Gainesville, FL, USA

- Abacavir Therapy and HLA-B*57:01 Genotype

Patel, Jai N., PharmD, BCOP; Levine Cancer Institute, Charlotte, NC, USA

- Irinotecan Therapy and UGT1A1 Genotype

Patrinos, George, PhD; University of Patras, Patra, Greece

- Fluorouracil Therapy and DPYD Genotype
- Risperidone Therapy and CYP2D6 Genotype
- Warfarin Therapy and VKORC1 and CYP Genotype

Pauli, Emily K., PharmD; Clearview Cancer Institute, Huntsville, AL, USA

- Capecitabine Therapy and DPYD Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype

Pawloski, Pamala, PharmD; HealthPartners Institute, Bloomington, MN, USA

- Dabrafenib Therapy and BRAF and G6PD Genotype
- Vemurafenib Therapy and BRAF and NRAS Genotype

Peeters, Marc, MD, PhD; University Hospital Antwerp, Antwerp, Belgium

- Panitumumab Therapy and RAS and BRAF Genotype

Petry, Natasha, PharmD, MPH, BCACP; North Dakota State University, Fargo, ND; Sanford Health Imagenetics, Sioux Falls, SD, USA

- Thioridazine Therapy and CYP2D6 Genotype
- Valbenazine Therapy and CYP2D6 Genotype

Phillips, Elizabeth, MD, FIDSA; Vanderbilt University Medical Center, Nashville, TN, USA

- Abacavir Therapy and HLA-B*57:01 Genotype

Pirmohamed, Munir, MB ChB (Hons), PhD, FRCP, FRCP(E), FFPM, FRSB, FBPhS, FMedSci; MRC Centre for Drug Safety Science and Wolfson Centre for Personalized Medicine, HDR UK North, British Pharmacological Society, University of Liverpool, Liverpool, UK

- Abacavir Therapy and HLA-B*57:01 Genotype
- Rasburicase Therapy and G6PD and CYB5R Genotype

Pollock, Bruce, MD, PhD; University of Toronto, Toronto, ON, Canada

- Venlafaxine Therapy and CYP2D6 Genotype

Pondé, Noam, MD; A.C. Camargo Cancer Center, São Paulo, Brazil

- Pertuzumab Therapy and ERBB2 (HER2) Genotype

Pratt, Victoria M., PhD, FACMG; Indiana University School of Medicine, Indianapolis, IN, USA

- Fluorouracil Therapy and DPYD Genotype
- Irinotecan Therapy and UGT1A1 Genotype
- Maraviroc Therapy and CCR5 Genotype
- Prasugrel Therapy and CYP Genotype

Price, Timothy, MBBS, DHlthSci (Medicine), FRACP; The Queen Elizabeth Hospital Campus, CALHN, Woodville South, Adelaide, Australia

- Panitumumab Therapy and RAS and BRAF Genotype

Punyawudho, Baralee, PhD; Chiang Mai University, Chiang Mai, Thailand

- Atazanavir Therapy and UGT1A1 Genotype

Purcell, Anthony, PhD; Monash University, Melbourne, Australia

- Abacavir Therapy and HLA-B*57:01 Genotype

Rahman, Shamima, PhD, FRCP; University College London, London, UK

- Gentamicin Therapy and MT-RNR1 Genotype

Ramey, Bronwyn, PhD, HCLD(ABB); LetsGetChecked, New York, NY, USA

- Atazanavir Therapy and UGT1A1 Genotype

Ramsey, Laura, PhD; University of Missouri-Kansas City School of Medicine, Kansas City, MO, USA

- Venlafaxine Therapy and CYP2D6 Genotype

Rashed, Rashed, BCNSP, MSc; Children’s Cancer Hospital, Cairo, Egypt

- Irinotecan Therapy and UGT1A1 Genotype

Rashed, Wafaa M., MSc, PhD; Ahram Canadian University, 6^th^ of October City, Egypt

- Sofosbuvir Therapy and IFNL4 Genotype

Reizine, Natalie, MD; University of Illinois Cancer Center, Chicago, IL, USA

- Belinostat Therapy and UGT1A1 Genotype
- Capecitabine Therapy and DPYD Genotype
- Oxycodone Therapy and CYP2D6 Genotype

Rendic, Slobodan, PhD; Independent Scientist, Zagreb, Croatia

- Hydroxychloroquine Therapy and G6PD Genotype

Riden, Katherine, PharmD; AccessDx Laboratory, Houston, TX, USA

- Primaquine Therapy and G6PD and CYP2D6 Genotype

Rimawi, Mothaffar Fahed, MD; Baylor College of Medicine, Houston, TX, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Rogawski, Michael, MD, PhD; University of California, Davis, CA, USA

- Brivaracetam Therapy and CYP2C19 Genotype
- Carbamazepine Therapy and HLA Genotype
- Clobazam Therapy and CYP2C19 Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype

Rosenzweig, Mark, PhD; Foundation Medicine Inc., Cambridge, MA, USA

- Dabrafenib Therapy and BRAF and G6PD Genotype
- Vemurafenib Therapy and BRAF and NRAS Genotype

Ross, Lisa, MS; ViiV Healthcare, Durham, NC, USA

- Abacavir Therapy and HLA-B*57:01 Genotype

Saab, Yolande, PharmD, PhD; Lebanese American University, Beirut, Lebanon

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Thioridazine Therapy and CYP2D6 Genotype

Sammons, Sarah, MD; Duke University, Durham, NC, USA

- Pertuzumab Therapy and ERBB2 (HER2) Genotype

Santos, Francisco Abad, MD, PhD; Hospital Universitario de la Princesa, Madrid, Spain

- Aripiprazole Therapy and CYP2D6 Genotype
- Tramadol Therapy and CYP2D6 Genotype

Saruwatari, Junji, PhD; Kumamoto University, Kumamoto, Japan

- Clobazam Therapy and CYP2C19 Genotype

Satyagraha, Ari Winasti, Dr. sc. hum.; Eijkman Institute for Molecular Biology, Jakarta, Indonesia

- Tafenoquine Therapy and G6PD Genotype

Schellens, Jan H.M., MD, PhD; The Netherlands Cancer Institute, Amsterdam, The Netherlands

- Capecitabine Therapy and DPYD Genotype

Scherf-Clavel, Maike, Dr. rer. Nat.; Center of Mental Health, University Hospital of Würzburg, Würzburg, Germany

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Schiff, Rachel, PhD; Baylor College of Medicine, Houston, TX, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Schiller, Emily, MD; Northern Light Health, Bangor, ME, USA

- Lecanemab Therapy and APOE Genotype

Schmidt, Siegfried O. F., MD, PhD, FAAFP; University of Florida Health Family Medicine, Gainesville, FL, USA

- Celecoxib Therapy and CYP2C9 Genotype
- Codeine Therapy and CYP2D6 Genotype
- Tramadol Therapy and CYP2D6 Genotype

Schneeweiss, Andreas, MD; Heidelberg University Hospital, Heidelberg, Germany

- Pertuzumab Therapy and ERBB2 (HER2) Genotype

Schroth, Werner, PhD; Institute of Clinical Pharmacology, Stuttgart, Germany

- Tamoxifen Therapy and CYP2D6 Genotype

Schuft, Kandace, PharmD; Wolters Kluwer, Hudson, OH, USA

- Atazanavir Therapy and UGT1A1 Genotype

Schulman, Sol, MD; Harvard Medical School, Boston, MA, USA

- Warfarin Therapy and VKORC1 and CYP Genotype

Scott, Stuart A., PhD, ABMGG, FACMG; Stanford University, Palo Alto, CA, USA

- Allopurinol Therapy and HLA-B*58:01 Genotype
- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Azathioprine Therapy and TPMT Genotype
- Celecoxib Therapy and CYP2C9 Genotype
- Clopidogrel Therapy and CYP2C19 Genotype
- Deutetrabenazine Therapy and CYP2D6 Genotype
- Diazepam Therapy and CYP2C19 Genotype
- Esomeprazole Therapy and CYP2C19 Genotype
- Flibanserin Therapy and CYP2C19 Genotype
- Gentamicin Therapy and MT-RNR1 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Lacosamide Therapy and CYP2C19 Genotype
- Mercaptopurine Therapy and TPMT and NUDT15 Genotype
- Omeprazole Therapy and CYP2C19 Genotype
- Pegloticase Therapy and G6PD Genotype
- Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype
- Rasburicase Therapy and G6PD and CYB5R Genotype
- Simeprevir Therapy and IFNL3 Genotype
- Tamoxifen Therapy and CYP2D6 Genotype
- Thioguanine Therapy and TPMT Genotype
- Venlafaxine Therapy and CYP2D6 Genotype

Shah, Shailja C., MD, MPH; Vanderbilt University Medical Center, Veterans Affairs Tennessee Valley Healthcare System, Nashville, TN, USA

- Omeprazole Therapy and CYP2C19 Genotype

Shaman, Jeff, PhD, MS; Coriell, Philadelphia, PA, USA

- Propafenone Therapy and CYP2D6 Genotype
- Simvastatin Therapy and SLCO1B1 Genotype

Sharma, Amit, PhD; ICGEB, New Delhi, India

- Primaquine Therapy and G6PD and CYP2D6 Genotype

Sharma, Priyanka, MD; University of Kansas Medical Center, Westwood, KS, USA

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

Shukla, Ashutosh M., MD; University of Florida and Veterans Health Care System, Gainesville, FL, USA

- Hydroxychloroquine Therapy and G6PD Genotype

Siasos, Gerasimos, MD, PhD, FCCP, FACC; Brigham and Women’s Hospital, Boston, MA, USA

- Clopidogrel Therapy and CYP2C19 Genotype

Singh, Jasvinder, MD, MPH; University of Alabama Birmingham, Gout Clinic at the University of Alabama Health Sciences Foundation, VA Medical Center, Birmingham, AL, USA

- Allopurinol Therapy and HLA-B*58:01 Genotype

Sissung, Tristan, PhD, MS; National Cancer Institute, Bethesda, MD, USA

- Belinostat Therapy and UGT1A1 Genotype

Skaar, Todd, PhD; Indiana University, Bloomington, IN, USA

- Codeine Therapy and CYP2D6 Genotype

Stavraka, Chara, MD, MRCP, PhD; King’s College London/Guy’s and St Thomas’ NHS Foundation Trust, London, UK

- Capecitabine Therapy and DPYD Genotype

Stamp, Lisa, MBChB, FRACP, PhD; University of Otago, Christchurch, New Zealand

- Allopurinol Therapy and HLA-B*58:01 Genotype

Stockis, Armel; UCB Pharma, Brussels, Belgium

- Brivaracetam Therapy and CYP2C19 Genotype

Sukasem, Chonlaphat, PhD; Mahidol University, Bangkok, Thailand

- Carbamazepine Therapy and HLA Genotype
- Risperidone Therapy and CYP2D6 Genotype

Sunthankar, Sudeep, MD, MSCI; Vanderbilt University Medical Center, Nashville, TN, USA

- Propafenone Therapy and CYP2D6 Genotype

Sweatt, J. David, PhD; Vanderbilt University, Nashville, TN, USA

- Pitt-Hopkins Syndrome

Szer, Jeff, B Med Sc, MB BS, FRACP; University of Melbourne, Peter MacCallum Cancer Centre and The Royal Melbourne Hospital, Melbourne, Australia

- Eliglustat Therapy and CYP2D6 Genotype

Tanasescu, Radu, MD; University of Nottingham School of Medicine, Queen’s Medical Centre, Nottingham, UK

- Siponimod Therapy and CYP2C9 Genotype

Thirumaran, Ranjit, MPharm, PhD; Genelex Labs, Seattle, WA, USA

- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Thompson, Alex, MD, PhD; Duke University Medical Centre, Durham, NC, USA

- Simeprevir Therapy and IFNL3 Genotype

Trenk, Dietmar, PhD; Albert Ludwig University of Freiburg, Freiburg, Germany

- Clopidogrel Therapy and CYP2C19 Genotype

Tsunedomi, Ryouichi, PhD; Yamaguchi University Graduate School of Medicine, Yamaguchi, Japan

- Irinotecan Therapy and UGT1A1 Genotype

Unadkat, Jashvant D., PhD; University of Washington, Seattle, WA, USA

- Dronabinol Therapy and CYP2C9 Genotype

Uppugunduri, Chakradhara, PhD, BPharm, MSc; University of Geneva, Geneva, Switzerland

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Celecoxib Therapy and CYP2C9 Genotype
- Flurbiprofen Therapy and CYP2C9 Genotype
- Diazepam Therapy and CYP2C19 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Lesinurad Therapy and CYP2C9 Genotype
- Piroxicam Therapy and CYP2C9 Genotype
- Warfarin Therapy and VKORC1 and CYP Genotype

van Laarhoven, Hanneke W.M., MD, PhD, PhD; University of Amsterdam, Amsterdam, The Netherlands

- Trastuzumab Therapy and ERBB2 (HER2) Genotype

van Rhenen, Mandy, MSc; Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype
- Fluorouracil Therapy and DPYD Genotype
- Metoprolol Therapy and CYP2D6 Genotype
- Omeprazole Therapy and CYP2C19 Genotype
- Propafenone Therapy and CYP2D6 Genotype
- Risperidone Therapy and CYP2D6 Genotype

Vieira, José Luiz Fernandes, PhD; Universidade Federal do Pará, Belém, Pará, Brazil

- Chloroquine Therapy and G6PD Genotype

Villain, Nicolas, MD, PhD; Sorbonne University, Pitié-Salpêtrière Hospital, Paris, France

- Lecanemab Therapy and APOE Genotype

Visk, DeeAnn, PhD; San Diego, CA, USA

- Propafenone Therapy and CYP2D6 Genotype

Wadelius, Mia, PhD; Uppsala University, Uppsala, Sweden

- Allopurinol Therapy and HLA-B*58:01 Genotype
- Atomoxetine Therapy and CYP2D6 Genotype
- Esomeprazole Therapy and CYP2C19 Genotype
- Irinotecan Therapy and UGT1A1 Genotype
- Omeprazole Therapy and CYP2C19 Genotype

Wainberg, Mark, PhD, OC, OQ, FRSC; McGill University, Montreal, QC, Canada

- Maraviroc Therapy and CCR5 Genotype

Walker, James, PharmD, MSPGx; PharmaGx Consultation, Wichita, KS, USA

- Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype
- Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Walton, Mollie M., MD; Children’s Mercy, Kansas City, MO, USA

- Metoprolol Therapy and CYP2D6 Genotype

Weinberg, Benjamin A., MD; MedStar Georgetown University Hospital, Georgetown Lombardi Comprehensive Cancer Center, Georgetown University Medical Center, Washington, DC, USA

- Panitumumab Therapy and RAS and BRAF Genotype

Whirl-Carrillo, Michelle, PhD; Stanford University, Stanford, CA, USA

- CYP2D6 Overview: Allele and Phenotype Frequencies

Wikistrand, John, MD, PhD; University of Gothenburg, Gothenbeg, Sweden

- Metoprolol Therapy and CYP2D6 Genotype

Woodward, Zachary, PharmD, Commander USPHS; U.S. Coast Guard Base Los Angeles-Long Beach, CA, USA

- Thioridazine Therapy and CYP2D6 Genotype
- Valbenazine Therapy and CYP2D6 Genotype

Wolowich, William R., PharmD; Nova Southeastern University, Fort Lauderdale, FL, USA

- Dronabinol Therapy and CYP2C9 Genotype

Yadlapati, Rena, MD, MSHS; University of California San Diego, San Diego, CA, USA

- Omeprazole Therapy and CYP2C19 Genotype

Yaeger, Rona, MD; Memorial Sloan Kettering Cancer Center, New York, NY, USA

- Dabrafenib Therapy and BRAF Genotype

Yin, Ji-Ye; Xiangya Hospital, Central South University, Changsha, Hunan Province, China

- Irinotecan Therapy and UGT1A1 Genotype

Zgheib, Nathalie K., MD; American University of Beirut, Beirut, Lebanon

- Mercaptopurine Therapy and TMPT and NUDT15 Genotype
- Valproic Acid Therapy and POLG Genotype

Zujewski, Jo Anne, MD; National Cancer Institute, Bethesda, MD, USA

- Pertuzumab Therapy and ERBB2 (HER2) Genotype