# Propafenone Therapy and CYP2D6 Genotype

## Introduction

Propafenone is an antiarrhythmic medication that belongs to class IC of antiarrhythmic agents. It acts on cardiac sodium channels to inhibit action potentials. In adults, it is used to prevent the reoccurrence of episodic atrial or ventricular fibrillation in individuals without underlying structural heart disease (propafenone may provoke proarrhythmic events in individuals with structural heart disease) It is also used to treat life-threatening ventricular arrhythmias. In pediatric individuals, propafenone can prevent and abort supraventricular tachycardias, most commonly orthodromic reciprocating tachycardia, or treat ventricular arrhythmias.

Propafenone is metabolized by CYP2D6, CYP3A4, and CYP1A2 enzymes. Approximately 6% of Caucasians in the United States of America are classified as a CYP2D6 poor metabolizer (PM) suggesting they may be at risk for increased drug levels (1). Medications that inhibit CYP2D6, CYP3A4, and CYP1A2 enzymes may also increase propafenone levels. Ongoing investigation aims to better understand the relationship between metabolizer status, propafenone drug levels, and adverse events, as these factors may not have a linear relationship.

A guideline from The Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Pharmacists Association provides dosing recommendations for propafenone based on CYP2D6 genotype. For CYP2D6 PMs, the guideline recommends reducing the initial dose of propafenone to 30%, electrocardiogram (ECG) monitoring, and monitoring plasma concentrations. For intermediate and ultrarapid metabolizers (UMs), the guideline states there is insufficient data to allow for a calculation of dose adjustment. Instead, it recommends adjusting the dose in response to plasma concentration, monitoring with ECG, being alert to side effects or reduced efficacy, or selecting an alternative drug (namely, one that is less dependent on CYP2D6 metabolism such as sotalol, disopyramide, quinidine, or amiodarone) (2, 3) (Table 1).

The US FDA-approved drug label for propafenone does not recommend an altered dosing regimen based on CYP2D6 metabolizer status. However, the label cautions against the simultaneous use of propafenone with both a CYP2D6 inhibitor and a CYP3A4 inhibitor due to the possibility of propafenone’s proarrhythmic effect and other cardiac and systemic adverse events (1) (Table 2). The label also states that the combination of CYP3A4 inhibition and CYP2D6 deficiency in propafenone users is potentially hazardous and the Table of Pharmacogenetic Associations states “ avoid propafenone use in PMs who are taking a CYP3A4 inhibitor” (1, 4).

The Health Canada-approved drug monograph similarly advises that individuals who are genetically determined “slow metabolizers” of propafenone (due to CYP2D6 variants leading to enzymatic deficiency) will experience higher plasma concentrations, which may result in clinically evident beta-blockade (5).

Table 1.

Therapeutic Recommendations for Propafenone based on CYP2D6 Phenotype, DPWG 2023

CYP2D6 phenotype | Recommendations for propafenone therapy
Ultrarapid metabolizer | Insufficient data to allow calculation of dose adjustment. Adjust dose in response to plasma concentration, record ECG, and be alert to reduced efficacy of therapy or select alternative drug that is hardly if at all metabolized by CYP2D6 (for example, sotalol, disopyramide, quinidine, amiodarone).
Intermediate metabolizer | Insufficient data to allow calculation of dose adjustment. Adjust dose in response to plasma concentration, record ECG and be alert to side effects or select alternative drug that is hardly if at all metabolized by CYP2D6 (for example, sotalol, disopyramide, quinidine, amiodarone).
Poor metabolizer | Reduce the dose to 30% of the standard dose, record ECG, monitor plasma concentration

Table adapted from (2, 3). DPWG - The Dutch Pharmacogenetics Working Group

Table 2.

Recommendations for Propafenone Based on CYP2D6 Status, FDA 2023

CYP2D6 status | Clinical impact | Recommendations
Concomitant CYP2D6 and CYP3A4 inhibiting medication(s) | Increased exposure to propafenone, may lead to cardiac arrythmias and exaggerated beta-adrenergic activity | Avoid propafenone use.
CYP2D6 poor metabolizer | Results in higher systemic concentrations and higher adverse reaction risk (arrhythmia). | Avoid use in poor metabolizers taking a CYP3A4 inhibitor.

Table adapted from (1, 4)

## Drug Class: Antiarrhythmics

Antiarrhythmic agents suppress abnormal heart rhythms (cardiac arrhythmias), which can originate from the atria (for example, atrial fibrillation, atrial flutter) or the ventricles (for example, ventricular tachycardia, ventricular fibrillation).

There are 5 main classes of antiarrhythmic agents, categorized based on their primary site of action (6):

- Class I: Block sodium (Na^+^) channels; for example, quinidine (class IA), lidocaine (class IB), propafenone (class IC)
- Class II: Block beta-adrenoreceptors; for example, carvedilol, metoprolol, propranolol
- Class III: Block potassium (K^+^) channels; for example, amiodarone, sotalol
- Class IV: Block calcium (Ca^2+^) channels; for example, verapamil, diltiazem
- Class V: Work through other or unknown mechanisms; for example, adenosine, digoxin

## Drug: Propafenone

Propafenone is an antiarrhythmic used to prevent the recurrence of atrial fibrillation in individuals with episodic atrial fibrillation or paroxysmal supraventricular tachycardia and no underlying structural heart disease. Propafenone is also used to manage paroxysmal supraventricular tachycardia, atrial flutter and life-threatening ventricular arrythmias (1). Atrial fibrillation is the most common type of harmful cardiac arrhythmia. It is more common in men than women, and the risk of developing atrial fibrillation increases with age. Atrial fibrillation may be paroxysmal (intermittent), persistent (lasting for at least 7 days), long-standing (more than 12 months), or permanent.

The symptoms of atrial fibrillation and paroxysmal supraventricular tachycardia range from no symptoms, dizziness, shortness of breath, palpitations, fainting, and chest pain. The pulse feels irregular, and an ECG shows an irregular rhythm. Atrial fibrillation increases the risk for reduced cardiac output, thrombosis, stroke, and death (7). Management typically includes antithrombotic therapy and rhythm control. Ventricular arrhythmias, which can lead to sudden cardiac death, may be managed with an implantable cardiac defibrillator, antiarrhythmic medications, catheter ablation, or a combination of these (8).

Propafenone must be taken every 8 hours and the initial low dose is titrated based on individual response and tolerance (1). The initial recommended dose is 150 mg (total of 450 mg per day), which can be increased after 3 to 4 days to 225 mg every 8 hours (675 mg daily). The maximum recommended dose is 300 mg every 8 hours (900 mg daily). (1, 5) Reduced dosages are recommended for individuals with significant changes to ECG measurements (for example, widening QRS complex or evidence of atrioventricular block). Individuals with mild to moderate hepatic insufficiency require significant dosage reductions to 150 mg once daily, then titrated up to 150 mg twice daily, 150 mg every 8 hours, and lastly 300 mg every 12 hours, with a minimum 4-day interval between each dose increase (5).

Propafenone is a class IC antiarrhythmic agent. All class I agents have a "membrane stabilizing effect"—by reducing the fast influx of sodium ions into the cardiac muscle cells, they inhibit the propagation of action potentials. Propafenone also has class II activity with beta-blocker effects, which can cause side effects such as fatigue, bradycardia, and bronchospasm (9, 10).

The class IC agents encainide and flecainide have been associated with an increased risk of cardiac arrest or death compared to placebo. Consequently, all class IC agents, including propafenone, are considered to have a proarrhythmic risk in individuals with structural heart disease. Propafenone is contraindicated in individuals with underlying structural heart disease, and should not be used in conditions such as heart failure, cardiogenic shock, conduction disorders, known Brugada syndrome (https://www.ncbi.nlm.nih.gov/medgen/222975), bradycardia, recent myocardial infarction (within the last 3 months), marked hypotension, bronchospastic disorders or severe obstructive pulmonary disease, and marked electrolyte imbalances (1, 11, 12, 13).

Although there are no well-controlled studies in pregnant women, the FDA-approved drug label states that data from decades of postmarketing experience and published case studies have “not identified any drug-associated risks of miscarriage, birth defects, or adverse maternal or fetal outcomes” (1). Propafenone and its metabolites are present in human milk, but no data exist on the effects of propafenone on breastfed infants or on milk production. Propafenone use by a nursing mother is not a reason to discontinue breastfeeding but should be used with caution, especially with newborn or preterm infants (14). According to the FDA-approved label, males of reproductive potential should be aware that propafenone may transiently impair spermatogenesis (1).

Clinical experience has not identified differences in response in elderly individuals compared to those under 65 years of age. However, the elderly population has a higher incidence of comorbidities, such as decreased hepatic or renal function and comedications, which may warrant cautious dosing (1). The FDA-approved drug label states that “safety and effectiveness of propafenone in pediatric [individuals] have not been established.” However, decades of clinical practice have demonstrated its benefit in this population (1, 15, 16, 17).

Propafenone is metabolized into 2 active metabolites: 5-hydroxypropafenone, formed by CYP2D6, and norpropafenone (N-depropylpropafenone), formed by both CYP3A4 and CYP1A2 (1). Studies have found that genetic variants in the CYP2D6 gene influence the plasma drug levels of propafenone (18, 19, 20, 21). The CYP2D6-derived metabolite 5-hydroxpropafenone is also classified as a class IC antiarrhythmic compound based on its action against sodium and calcium channels, although it is less effective in beta-blockade than the parent compound (1, 22, 23, 24). It was found to have a relative potency of 80% compared to propafenone in a rat model of reperfusion arrhythmia (25). In contrast, norpropafenone has weaker sodium channel activity but similar affinity for beta-receptors (1).

In individuals who lack CYP2D6 activity, metabolism of propafenone is slower, so the 5-hydroxy metabolite is not formed or is formed at very slow rates. In these individuals, high doses of propafenone (850 mg daily) lead to plasma concentrations approximately double those in individuals with normal CYP2D6 activity. At lower initial doses, the difference on concentrations between propafenone and its 5-hydroxy metabolite is even greater (1, 26).

The FDA recommends the same dosing regimen for all individuals regardless of their CYP2D6 activity levels. This is because, even at high doses, the effects of higher propafenone levels are mitigated by the lack of the active 5-hydroxy metabolite in the PMs, and because steady-state conditions are achieved after 4 to 5 days of titrating the dose in all individuals. No clear association between propafenone drug or metabolite levels and adverse events has been established; therefore, dosing titration should be guided by efficacy, adverse events, ECG monitoring, with attention to clinical and ECG evidence of toxicity (1).

The FDA-approved drug label for propafenone cautions against simultaneous use of propafenone with both a CYP2D6 inhibitor and a CYP3A4 inhibitor, as the combination of CYP3A4 inhibition and either CYP2D6 inhibition or deficiency may increase propafenone exposure and predispose individuals to proarrhythmic events (1).

## Gene: CYP2D6

The CYP450 family is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are highly polymorphic and can result in decreased, absent, or increased enzyme activity. One prominent cytochrome P450 member, CYP2D6, is responsible for the metabolism of many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### The CYP2D6 Alleles

The CYP2D6 gene is highly polymorphic, with over 170 star (*) alleles described and cataloged by the Pharmacogene Variation (PharmVar) Consortium. Each allele is associated with either normal, decreased, or absent enzyme function (Table 3) (27, 28). Star alleles are defined by the variants detected on one chromosome (haplotype).

The combination of CYP2D6 haplotypes a person has determines their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele is assigned an activity score from 0 to 1, which in turn is then used to assign a phenotype of metabolizer status (for example, CYP2D6 PM). However, the activity score system is not standardized across all clinical laboratories or genotyping platforms, leading to variability in results. To address this, the CPIC and DPWG have created a consensus activity score guideline for CYP2D6 phenotype. The CYP2D6 phenotype is predicted from the diplotype activity score, calculated as the sum of the allele score values, which usually ranges from 0 to 3.0: (29)

- An UM has an activity score greater than 2.25
- A normal metabolizer phenotype (NM) has an activity score of 1.25–2.25
- An intermediate metabolizer (IM) has an activity score of >0–<1.25
- A PM has an activity score of 0

Table 3.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *34, *39 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6) and (28). Activity scores from (29).

The CYP2D6*1 allele is the wild-type allele when no variants are detected and is associated with normal enzyme activity and the NM phenotype. The CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, and *6) (30, 31) or an enzyme with decreased activity (for example, *10, *17, and *41) (28, 32) (see Table 3). There are significant inter-ethnic differences in the frequency of these alleles. For instance, *3, *4, *6, and *41 are more common in individuals with European ancestry, *17 is more frequent in individuals of African ancestry, and *10 is prevalent in those of Asian ancestry. (33)

Larger structural variants at the CYP2D6 locus have also been described, including gene duplications, deletions, tandem alleles, gene hybrids (namely, CYP2D6-CYP2D7), and gene conversions. As expected, deletions result in a no-function allele (for example, the CYP2D6*5 allele is a deletion). Duplications have been reported for alleles with normal function and decreased function. In the case of allele duplications, the activity scores for the full complement of CYP2D6 alleles are summed to determine the predicted metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (34).

The frequency of the CYP2D6 star alleles with altered function varies across global populations, resulting in different frequencies of the resulting metabolizer phenotype. Given CYP2D6’s role in the metabolism of many drugs, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency for normal-function star alleles, resulting in a large proportion of individuals classified as NMs. However, decreased-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, resulting in a higher proportion of IM phenotype individuals in this ancestral group. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, which are associated with lower metabolizer scores in these individuals.

The frequency of UM phenotypes is notably high in certain regions, including northern Africa, (particularly Algeria), the mestizo Columbian population, the Druze ancestry group from the Middle East, and non-Austronesian Melanesian populations (35, 36). Given the distribution of duplicated, functional CYP2D6 alleles, it has been proposed that a gene duplication event arose in populations based in the region of Saudi Arabia-Ethiopia, then spread through migration along the Mediterranean, resulting in a higher frequency of UM phenotype in the ancestral populations from these regions (37, 38).

More detailed information on published allele and phenotype frequencies can be found in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Factors other than genotype can affect CYP2D6 enzyme activity and, consequently, an individual’s metabolizer phenotype. Administration of an interacting medication can lead to a phenomenon called phenoconversion, in which a genotype-based metabolizer status is altered due to concomitant enzyme inhibition or activation. Published data indicate that 17–25% of individuals are impacted by phenoconversion (39).

The enzymatic activity of CYP2D6 can be inhibited or reduced by medications including, but not limited to strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, as well as moderate inhibitors like duloxetine (40, 41). This inhibition can result in NMs or IMs responding to medications as if they were PMs, depending upon the strength of the enzyme inhibition. Strong inhibitors can completely inhibit CYP2D6, while moderate inhibitors can reduce activity by 50%. Co-medication with multiple strong or moderate CYP2D6 inhibitors may result in reduced metabolism of drug substrates, a phenomenon commonly observed in psychiatric pharmacotherapy (42, 43).

Conversely, discontinuing a CYP2D6 inhibitor can revert an individual's CYP2D6 activity to their genetically predicted phenotype baseline. Integration of CYP2D6 phenoconversion into clinical practice requires knowledge of multiple clinical factors, and tools have been developed to support clinicians (44).

## Linking CYP2D6 Genetic Variation with Treatment Response

A meta-analysis of pharmacokinetic (PK) data determined that significant differences exist between individuals classified as CYP2D6 NM or PM with respect to the maximum plasma concentration, total exposure, and plasma half-life of propafenone when dosed at 300 mg (45). One study included in this meta-analysis reported that the plasma levels of 5-hydroxypropafenone were below the limits of detection in their PM subjects, though propafenone levels remained higher than those of NM or IM subjects (46). Another study conducted in Japan also observed that individuals with no-function (PM) CYP2D6 alleles had higher plasma propafenone levels relative to NM or IM individuals. Additionally, the CYP2D6*10 allele, which typically leads to an IM phenotype, was not associated with changes in propafenone PK (47).

While FDA labeling states that differences in CYP2D6 activity are not clinically relevant once steady-state plasma levels of propafenone are reached, it has been reported that healthy individuals with a CYP2D6 PM phenotype exhibited higher plasma levels of propafenone relative to NM individuals over the course of a multi-day study (26). However, differences in beta-blockade between NM and PM individuals were only observed at lower propafenone doses, suggesting that metabolizer status may not significantly impact efficacy at therapeutic doses (26). It is possible that PM individuals experienced higher beta-blockade than NMs due to abundance of the parent compound or the norpropafenone metabolite (which is not dependent upon CYP2D6 activity). Nonetheless, the study authors proposed that propafenone itself was the primary contributing compound to the beta-blockade effect (26).

Changes in propafenone exposure may affect the risk of adverse effects, leading some authors to recommend preemptive CYP2D6 testing before therapy initiation (45). A retrospective analysis of pediatric and young adult cases reported an inverse correlation between the total number of adverse events with propafenone therapy and CYP2D6 activity score. Those with lower CYP2D6 activity scores had a higher incidence of systemic adverse events, but no difference in cardiac adverse events was observed (48).

## Genetic Testing

The NIH’s Genetic Testing Registry (GTR) lists genetic tests available for propafenone response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN078001) and the CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5Bgeneid%5D). The available CYP2D6 tests include targeted single-gene tests as well as multi-gene panels. In addition, variant CYP2D6 alleles to be included in clinical genotyping assays have been recommended by the Association for Molecular Pathology (AMP) (49). For CYP2D6, the AMP recommends that the minimum panel of variant alleles include *2, *3, *4, *5, *6, *9, *10, *17, *29, *41, and copy number interrogation.

Results are typically reported as a diplotype, such as CYP2D6 *1/*1 (wild type). A copy number result, if available, is also important when interpreting CYP2D6 results (50, 51). When individuals have more than 2 copies of CYP2D6, the copies of the allele are denoted by “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6*1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use the notation of “DUP” to indicate an increase in copy number, but the report does not always specify the number of duplications or the allele that has been duplicated due to technical limitations. The test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be confirmed by checking the diplotype and calculating the CYP2D6 activity score, as described in the “CYP2D6 Alleles” section above.

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in a real-world clinical setting (52, 53, 54). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, as gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (55).

## The CYP2D6 Gene Interactions with Medications Used for Additional Indications

The CYP family of enzymes is involved in the metabolism of many substances, and CYP2D6, in particular, has been implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

- Antipsychotics—For example, aripiprazole, risperidone, thioridazine and—to a lesser extent—clozapine are metabolized by CYP2D6. According to the FDA, aripiprazole dosage should be reduced for PMs, and thioridazine is contraindicated for individuals known to have reduced CYP2D6 activity due to an increased risk of potentially fatal side effects. The UMs may have a decreased plasma concentration of risperidone, per DPWG recommendations.
- Tricyclic antidepressants—For example, amitriptyline and imipramine may require alternative therapies or dosage adjustments, potentially guided by therapeutic drug monitoring, to achieve the desired therapeutic range in UMs or PMs. Ultimately, tricyclic antidepressants may be ineffective in CYP2D6 UMs, depending on the indication and dosage used.
- Serotonin and norepinephrine reuptake inhibitors—For example atomoxetine and venlafaxine may have reduced efficacy in UMs at standard doses, while PMs are at risk of elevated plasma concentrations for both medications. The DPWG advises against the use of venlafaxine in CYP2D6 PMs and IMs.
- Anticancer medications—For example, tamoxifen is activated by CYP2D6, and IMs or PMs may derive reduced benefit from tamoxifen therapy.
- Pain management—For example, codeine and tramadol are prodrugs that require activation by CYP2D6 to achieve the desired analgesic effect.
- Therapies for genetic disorders—For example, eliglustat, used in the treatment of Gaucher disease, and deutetrabenazine, used in the treatment of Huntington disease and tardive dyskinesia, have reduced dose recommendations for CYP2D6 PMs. The CYP2D6 UMs may not achieve adequate concentrations of eliglustat; therefore, CYP2D6 genotyping is required initiating eliglustat therapy.

It is important to note that CYP2D6 is the most common biomarker for drug responses in FDA drug labels; the list provided here is by no means exhaustive. Additional information on gene-drug interactions for CYP2D6 are available from the Pharmacogenomics Knowledgebase (https://www.pharmgkb.org/gene/PA128), CPIC (https://cpicpgx.org/genes-drugs/) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2023 Statement from the US Food and Drug Administration (FDA):

The combination of cytochrome P450 3A4 (CYP3A4) inhibition and either cytochrome P450 2D6 (CYP2D6) deficiency or CYP2D6 inhibition with the simultaneous administration of propafenone may significantly increase the concentration of propafenone and thereby increase the risk of proarrhythmia and other adverse events. Therefore, avoid simultaneous use of propafenone hydrochloride tablets with both a CYP2D6 inhibitor and a CYP3A4 inhibitor.

[…]

Propafenone is metabolized by CYP2D6, CYP3A4, and CYP1A2 isoenzymes. Approximately 6% of Caucasians in the U.S. population are naturally deficient in CYP2D6 activity and other demographic groups are deficient to a somewhat lesser extent. Drugs that inhibit these CYP pathways (such as desipramine, paroxetine, ritonavir, sertraline for CYP2D6; ketoconazole, erythromycin, saquinavir, and grapefruit juice for CYP3A4; and amiodarone and tobacco smoke for CYP1A2) can be expected to cause increased plasma levels of propafenone.

Increased exposure to propafenone may lead to cardiac arrhythmias and exaggerated beta-adrenergic blocking activity. Because of its metabolism, the combination of CYP3A4 inhibition and either CYP2D6 deficiency or CYP2D6 inhibition in users of propafenone is potentially hazardous. Therefore, avoid simultaneous use of propafenone hydrochloride with both a CYP2D6 inhibitor and a CYP3A4 inhibitor.

Table of Pharmacogenetic Associations, Section 1.

Drug | Gene | Affected Subgroups | Description of Gene-Drug Interaction
Propafenone | CYP2D6 | poor metabolizers | Results in higher systemic concentrations and higher adverse reaction risk (arrhythmia). Avoid use in poor metabolizers taking a CYP3A4 inhibitor.

Please review the complete therapeutic recommendations that are located here: (1, 4)

2023 Summary of recommendations from The Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Pharmacists Association (KNMP):

CYP2D6 PM: propafenon

Genetic variation increases the sum of the plasma concentrations of propafenone and the active metabolite 5-hydroxypropafenone. This increases the risk of side effects.

Recommendation:

1 Reduce the dose to 30% of the standard dose, perform an ECG and monitor plasma concentrations

CYP2D6 IM: propafenon

Genetic variation increases the sum of the plasma concentrations of propafenone and the active metabolite 5-hydroxypropafenone. This may increase the risk of side effects.

Recommendation:

It is not possible to offer adequately substantiated recommendations for dose adjustment based on the literature.

1 Either guide the dose by therapeutic drug monitoring, perform an ECG and be alert to side effects
2 Or choose an alternative

Antiarrhythmic drugs that are hardly if at all metabolised by CYP2D6 include, for example, sotalol, disopyramide, quinidine and amiodarone.

CYP2D6 UM: propafenon

Genetic variation decreases the sum of the plasma concentrations of propafenone and the active metabolite 5-hydroxypropafenone. This increases the risk of reduced or no efficacy.

Recommendation:

It is not possible to offer adequately substantiated recommendations for dose adjustment based on the literature.

1 Either monitor plasma concentrations, perform an ECG and be alert to reduced efficacy of the therapy.
2 Or choose an alternative

Antiarrhythmic drugs that are hardly if at all metabolised by CYP2D6 include, for example, sotalol, disopyramide, quinidine and amiodarone.

Please review the complete therapeutic recommendations that are located here: (3).

## Nomenclature of Selected CYP2D6 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A + 1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (56)

^[2]^ AMP Tier 2 allele, (56)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (57).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (58).

AMP - Association for Molecular Pathology

## Acknowledgments

Version 1.0 (April 2017)

The author would like to thank the following individuals for reviewing this summary: John T. Callaghan, MD, PhD, Associate Dean of Veterans Affairs Research, Associate Professor of Medicine, and Pharmacology and Toxicology, Department of Veterans Affairs, and Indiana University School of Medicine, Indianapolis, IN, USA ; Ben Kong, PharmD, BCPS, Clinical Pharmacist, Oregon Health & Science University, Portland, OR, USA; Gouri Mukerjee, Scientific Officer at Geneyouin Inc., Toronto, ON, Canada; Mohamed Nagy, Clinical Pharmacist, Head of the Personalised Medication Management Unit, Department of Pharmaceutical Services, Children's Cancer Hospital, Cairo, Egypt; Mandy van Rhenen, Secretary of the Dutch Pharmacogenetics Working Group (DPWG), Centre for Information on Medicines, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; and DeeAnn Visk, PhD, a medical writer, editor, and member of the Clinical Pharmacogenetics Implementation Consortium (CPIC), Poway, CA, USA.

Version 2.0 (April 2025)

The author would like to thank Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; Jeffrey A. Shaman, PhD, MS, Chief Science Officer, Coriell Life Sciences, Philadelphia, PA, USA; and Sudeep Sunthankar, MD, MSCI, Assistant Professor of Pediatrics, Cardiology, Vanderbilt University Medical Center, Nashville, TN, USA for reviewing this summary.

## Version History

Version 1.0 of this article was published on April 4, 2017 and is available here.

Version 2.0 of this article was published on April 14, 2025. An updated reference to the FDA-approved drug label, references to international drug labeling information (Health Canada) and the most recent Dutch Pharmacogenetic Working Group dosing recommendations are included. Guidance from the Association for Molecular Pathology regarding CYP2D6 variants to include on pharmacogenetic testing were added to this version. Descriptions of CYP2D6 variation, activity scoring from international consensus publications, and expanded allele nomenclature were also incorporated during the update to reflect the current knowledge. There is no change in the regulatory or professional recommendations for dosing propafenone based on CYP2D6 genotype relative to the prior version of this chapter.

## References

1 PROPAFENONE HYDROCHLORIDE tablet, film coated. East Windsor, NJ, USA: Aurobindo Pharma Limited; 2023. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=0c887381-42fe-4f37-858a-d9ffb218dd1c.
2 Swen, J.J., M. Nijenhuis, A. de Boer, L. Grandia, et al., Pharmacogenetics: from bench to byte--an update of guidelines. Clin Pharmacol Ther, 2011. 89(5): p. 662-73.21412232
3 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. Pharmacogenetic Recommendation Text (Version 2) [Cited September 2024]. Available from https://www.knmp.nl/dossiers/farmacogenetica.
4 FDA, U. Table of Pharmacogenetic Associations. 2022 10/26/2022 [cited 2024; Available from: https://www.fda.gov/medical-devices/precision-medicine/table-pharmacogenetic-associations#section3.
5 Product Monograph APO-PROPAFENONE, Propafenone hydrochloride tablets. Toronto, Ontario, Canada: INC., A.; 2023. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=67227.
6 Vaughan Williams, E.M., A classification of antiarrhythmic actions reassessed after a decade of new drugs. J Clin Pharmacol, 1984. 24(4): p. 129-47.6144698
7 Andersson, T., A. Magnuson, I.L. Bryngelsson, O. Frobert, et al., All-cause mortality in 272,186 patients hospitalized with incident atrial fibrillation 1995-2008: a Swedish nationwide long-term case-control study. Eur Heart J, 2013. 34(14): p. 1061-7.23321349
8 Larson, J., L. Rich, A. Deshmukh, E.C. Judge, and J.J. Liang, Pharmacologic Management for Ventricular Arrhythmias: Overview of Anti-Arrhythmic Drugs. J Clin Med, 2022. 11(11).35683620
9 Stoschitzky, K., G. Stoschitzky, P. Lercher, H. Brussee, et al., Propafenone shows class Ic and class II antiarrhythmic effects. Europace, 2016. 18(4): p. 568-71.26056191
10 Darbar, D. and D.M. Roden, Pharmacogenetics of antiarrhythmic therapy. Expert Opin Pharmacother, 2006. 7(12): p. 1583-90.16872261
11 Echt, D.S., P.R. Liebson, L.B. Mitchell, R.W. Peters, et al., Mortality and morbidity in patients receiving encainide, flecainide, or placebo. The Cardiac Arrhythmia Suppression Trial. N Engl J Med, 1991. 324(12): p. 781-8.1900101
12 Vaughan Williams, E.M., Significance of classifying antiarrhythmic actions since the cardiac arrhythmia suppression trial. J Clin Pharmacol, 1991. 31(2): p. 123-35.1901320
13 Lin, C.Y., Y.J. Lin, L.W. Lo, Y.Y. Chen, et al., Factors predisposing to ventricular proarrhythmia during antiarrhythmic drug therapy for atrial fibrillation in patients with structurally normal heart. Heart Rhythm, 2015. 12(7): p. 1490-500.25889809
14 Propafenone, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000141.
15 Paul, T. and J. Janousek, New antiarrhythmic drugs in pediatric use: propafenone. Pediatr Cardiol, 1994. 15(4): p. 190-7.7991437
16 Paul, T., H. Bertram, R. Bokenkamp, and G. Hausdorf, Supraventricular tachycardia in infants, children and adolescents: diagnosis, and pharmacological and interventional therapy. Paediatr Drugs, 2000. 2(3): p. 171-81.10937468
17 Bink-Boelkens, M.T., Pharmacologic management of arrhythmias. Pediatr Cardiol, 2000. 21(6): p. 508-15.11050274
18 Cai, W.M., J. Xu, B. Chen, F.M. Zhang, et al., Effect of CYP2D6*10 genotype on propafenone pharmacodynamics in Chinese patients with ventricular arrhythmia. Acta Pharmacol Sin, 2002. 23(11): p. 1040-4.12421483
19 Chen, B. and W.M. Cai, Influence of CYP2D6*10B genotype on pharmacokinetics of propafenone enantiomers in Chinese subjects. Acta Pharmacol Sin, 2003. 24(12): p. 1277-80.14653957
20 Zhou, S.F., Polymorphism of human cytochrome P450 2D6 and its clinical significance: Part I. Clin Pharmacokinet, 2009. 48(11): p. 689-723.19817501
21 Su, Y., B.Q. Liang, Y.L. Feng, Y. Zhan, et al., Assessment of 25 CYP2D6 alleles found in the Chinese population on propafenone metabolism in vitro. Can J Physiol Pharmacol, 2016. 94(8): p. 895-9.27203132
22 Valenzuela, C., C. Delgado, and J. Tamargo, Electrophysiological effects of 5-hydroxypropafenone on guinea pig ventricular muscle fibers. J Cardiovasc Pharmacol, 1987. 10(5): p. 523-9.2447400
23 Delgado, C., J. Tamargo, T. Tejerina, and C. Valenzuela, Effects of 5-hydroxy-propafenone in guinea-pig atrial fibres. Br J Pharmacol, 1987. 90(3): p. 575-82.2882804
24 Franqueza, L., C. Valenzuela, E. Delpon, M. Longobardo, et al., Effects of propafenone and 5-hydroxy-propafenone on hKv1.5 channels. Br J Pharmacol, 1998. 125(5): p. 969-78.9846634
25 Oti-Amoako, K., S. Vozeh, H.R. Ha, and F. Follath, The relative potency of major metabolites and enantiomers of propafenone in an experimental reperfusion arrhythmia model. J Cardiovasc Pharmacol, 1990. 15(1): p. 75-81.1688986
26 Lee, J.T., H.K. Kroemer, D.J. Silberstein, C. Funck-Brentano, et al., The role of genetically determined polymorphic drug metabolism in the beta-blockade produced by propafenone. N Engl J Med, 1990. 322(25): p. 1764-8.1971708
27 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154-170.31544239
28 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399-401.29134625
29 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215-223.27441996
30 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256-63.8287064
31 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6-13.15492763
32 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 26 Sept 2016]. Available from https://www.pharmgkb.org/haplotype/PA165816582.
33 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229-43.11972444
34 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
35 Koopmans, A.B., M.H. Braakman, D.J. Vinkers, H.W. Hoek, and P.N. van Harten, Meta-analysis of probability estimates of worldwide variation of CYP2D6 and CYP2C19. Transl Psychiatry, 2021. 11(1): p. 141.33627619
36 A, P.S., P. Dorado, A. Borbon, F. de Andres, et al., High prevalence of CYP2D6 ultrarapid metabolizers in a mestizo Colombian population in relation to Hispanic mestizo populations. Pharmacogenomics, 2020. 21(17): p. 1227-1236.
37 Ingelman-Sundberg, M., Pharmacogenetics: an opportunity for a safer and more efficient pharmacotherapy. J Intern Med, 2001. 250(3): p. 186-200.11555122
38 Aklillu, E., K. Herrlin, L.L. Gustafsson, L. Bertilsson, and M. Ingelman-Sundberg, Evidence for environmental influence on CYP2D6-catalysed debrisoquine hydroxylation as demonstrated by phenotyping and genotyping of Ethiopians living in Ethiopia or in Sweden. Pharmacogenetics, 2002. 12(5): p. 375-83.12142727
39 Cicali, E.J., D.M. Smith, B.Q. Duong, L.G. Kovar, et al., A Scoping Review of the Evidence Behind Cytochrome P450 2D6 Isoenzyme Inhibitor Classifications. Clin Pharmacol Ther, 2020. 108(1): p. 116-125.31910286
40 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842-1850.30670877
41 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933-939.29882961
42 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024. 29(11): p. 3495-3502.38783055
43 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
44 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677-687.34231197
45 Tran, Q.T., I.H. Baek, N.Y. Han, H.Y. Yun, and J.W. Chae, The Effect of CYP2D6 Phenotypes on the Pharmacokinetics of Propafenone: A Systematic Review and Meta-Analysis. Pharmaceutics, 2022. 14(7).35890339
46 Rouini, M.R. and M. Afshar, Effect of CYP2D6 polymorphisms on the pharmacokinetics of propafenone and its two main metabolites. Therapie, 2017. 72(3): p. 373-382.28087064
47 Doki, K., Y. Shirayama, Y. Sekiguchi, K. Aonuma, et al., Effect of CYP2D6 genetic polymorphism on peak propafenone concentration: no significant effect of CYP2D6*10. Pharmacogenomics, 2020. 21(18): p. 1279-1288.33203295
48 Sunthankar, S.D., P.J. Kannankeril, A. Gaedigk, A.E. Radbill, et al., Influence of CYP2D6 genetic variation on adverse events with propafenone in the pediatric and young adult population. Clin Transl Sci, 2022. 15(7): p. 1787-1795.35514162
49 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and the European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021. 23(9): p. 1047-1064.34118403
50 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127-34.25974703
51 Jarvis, J.P., A.P. Peter, and J.A. Shaman, Consequences of CYP2D6 Copy-Number Variation for Pharmacogenomics in Psychiatry. Front Psychiatry, 2019. 10: p. 432.31281270
52 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, and C. Ryan, Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89-99.35194175
53 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094-3118.34474980
54 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347-356.36739136
55 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116-3125.37277227
56 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.34118403
57 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564-9.26931183
58 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, and T.E. Klein, Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542-545.34091888

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Aripiprazole Therapy and CYP2D6 Genotype

Atomoxetine Therapy and CYP2D6 Genotype

CYP2D6 Overview: Allele and Phenotype Frequencies

Carvedilol Therapy and CYP2D6 Genotype

Clozapine Therapy and CYP Genotype

Codeine Therapy and CYP2D6 Genotype

Deutetrabenazine Therapy and CYP2D6 Genotype

Eliglustat Therapy and CYP2D6 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Metoprolol Therapy and CYP2D6 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Primaquine Therapy and G6PD and CYP2D6 Genotype

Risperidone Therapy and CYP2D6 Genotype

Tamoxifen Therapy and CYP2D6 Genotype

Thioridazine Therapy and CYP2D6 Genotypes

Tramadol Therapy and CYP2D6 Genotype

Valbenazine Therapy and CYP2D6 Genotype

Venlafaxine Therapy and CYP2D6 Genotype

## Tests in GTR by Condition

Propafenone response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN078001&term=CN078001[DISCUI]&display_string=Propafenone response)

## Tests in GTR by Gene

CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1565[geneid]+AND+CN078001[cui])