# Prasugrel Therapy and CYP Genotype

## Introduction

Prasugrel (also known as Efient) is a third-generation thienopyridine platelet inhibitor used in individuals with acute coronary syndrome (ACS) undergoing percutaneous coronary intervention (PCI). Prasugrel is prescribed to reduce thrombotic cardiovascular events, such as stent thrombosis, myocardial infarction, and stroke in these individuals. Along with other antiplatelet agents such as clopidogrel and ticagrelor, prasugrel inhibits platelet activation by irreversibly binding to the platelet receptor, P2RY12. (1)

Prasugrel is metabolized into its active metabolite primarily by CYP3A5 and CYP2B6, and to a lesser extent by CYP2C9 and CYP2C19. The FDA-approved label for prasugrel states that genetic variations in CYP2B6, CYP2C9, CYP2C19, or CYP3A5 genes do not significantly affect prasugrel’s pharmacokinetics, the generation of its active metabolite, or its inhibition of platelet aggregation in healthy subjects, individuals with stable atherosclerosis, or those with ACS (1).

Another commonly prescribed antiplatelet agent is the second-generation thienopyridine clopidogrel, which is bioactivated primarily by CYP2C19. As a result,, clopidogrel is less effective in individuals with decreased or non-function variant alleles of the CYP2C19 gene. In contrast, CYP2C19 variants do not decrease the effectiveness of prasugrel, which is a more potent antiplatelet agent compared to clopidogrel, though it carries a higher risk of bleeding (2, 3, 4, 5).

## Drug: Prasugrel

Prasugrel is a third-generation thienopyridine antiplatelet agent that binds irreversibly to the P2RY12 receptor and inhibits adenosine diphosphate (ADP)-mediated platelet activation and aggregation. Other P2RY12 receptor blockers include clopidogrel and ticagrelor.

As an antiplatelet agent, prasugrel inhibits the formation of blood clots in the coronary, peripheral, and cerebrovascular arteries among individuals with ACS.

A decrease in blood flow in the coronary arteries, known as ACS, includes unstable angina, which occurs suddenly, often at rest or with minimal exertion. Unstable angina may be new in onset or may occur with less exertion than previously. Another form of ACS is a myocardial infarction (MI), which may be classified as ST-segment elevation myocardial infarction (STEMI), or non-ST-segment elevation myocardial infarction (NSTEMI) based on electrocardiogram (EKG) findings. A STEMI is identified when EKG findings show ST-segment elevation. If no ST-segment elevation is present but myocardial biomarkers such as troponin I or T are increased, the term NSTEMI is applied.

Individuals with ACS are usually treated with a P2Y12 receptor blocker and aspirin (dual antiplatelet therapy, DAPT) to reduce the risk of developing a coronary artery thrombus. Platelet adhesion and aggregation are early stages in thrombus formation, which may occlude the coronary artery. Individuals who undergo PCI are at risk of stent occlusion via this mechanism.

The TRITON-TMI 38 trial compared prasugrel with clopidogrel in 13,608 individuals with ACS undergoing PCI. Prasugrel provided more potent platelet inhibition than clopidogrel: after 15 months, individuals treated with prasugrel had a lower incidence of cardiovascular death, nonfatal MI, or nonfatal stroke as compared with those treated with clopidogrel (9.9% versus 12.1%) (2, 3). However, prasugrel was associated with a higher risk of bleeding, leading to the FDA warning that its use is contraindicated in individuals with active pathological bleeding or a history of stroke or transient ischemic attack (TIA) (4, 5).

Prasugrel inhibits ADP-induced platelet aggregation by selectively binding to P2RY12. As a pro-drug, prasugrel requires conversion into its active metabolite to function as an antiplatelet agent. It is rapidly metabolized to thioacetone, which is further converted to an active metabolite by CYP3A5 and CYP2B6, and to a lesser extent by CYP2C9 and CYP2C19.

The active prasugrel metabolite (R-138727) contains a reactive thiol group that forms a disulfide bridge with a free cysteine residue on the P2RY12 receptor. Once irreversibly bound to prasugrel, the receptor is unable to bind ADP, and platelet activation via this pathway is prevented for the platelet’s lifespan, approximately 10 days (6).

Despite the general efficacy of clopidogrel, interindividual variability in metabolite levels, platelet inhibition, and clinical response has been observed. It has been estimated that between 16–50% of individuals treated with clopidogrel exhibit high on-treatment platelet reactivity (HTPR), meaning that some P2RY12 receptors remain unblocked (7). This is partially due to genetic variants in the CYP2C19 gene, which encodes the enzyme responsible for converting clopidogrel to its active metabolite. Individuals with no-function CYP2C19 alleles (for example, CYP2C19*2) have reduced plasma levels of the active clopidogrel metabolites and an increased risk for HTPR.

In contrast, genetic variation in CYP3A5, CYP2B6, CYP2C9, or CYP2C19 does not have a relevant effect on the prasugrel pharmacokinetics, active metabolite formation, or platelet aggregation inhibition(8, 9, 10, 11, 12). Therefore, although both clopidogrel and prasugrel form active metabolites with similar potency, prasugrel is a more potent antiplatelet agent due to its more efficient active metabolite formation (13).

While prasugrel is more effective than standard-dose clopidogrel, DAPT with clopidogrel and aspirin remains the standard of care at some institutions for certain ACS individuals undergoing PCI (14). This preference is mainly because clopidogrel has a lower bleeding risk and is less expensive (15). However, the availability of CYP2C19 genetic testing allows for personalized antiplatelet therapy, where individuals with impaired CYP2C19 activity can be identified and offered an alternative antiplatelet agent, such as prasugrel (16, 17, 18, 19). Recent studies have shown that CYP2C19-genotype guided antiplatelet therapy results in the therapeutic goal of reduced on-treatment platelet reactivity more frequently than standard therapy (20, 21, 22), which may also be cost-effective in ACS individuals undergoing PCI (23).

## The Cytochrome P450 Superfamily

The cytochrome P450 superfamily (CYP450) is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs. The CYP450 genes are highly polymorphic, which can result in no, decreased, normal, or increased enzyme activity.

The CYP2C19, CYP2C9, CYP3A5, and CYP2B6 enzymes are involved in the metabolism of prasugrel, but genetic variations in these genes do not appear to influence the pharmacokinetics of prasugrel. In contrast, genetic variation in the CYP2C19 gene may lead to decreased effectiveness of the related drug clopidogrel. For more information on CYP variants and the clopidogrel drug response, see “Clopidogrel Therapy and CYP2C19 Genotype”.

Conversely, administration of prasugrel is not expected to impact the efficacy of other medications that depend on CYP2C19, CYP2C9, CYP3A5, or CYP2B6 metabolism, despite in vitro assays showing an induction of CYP3A enzymes (1, 24, 25).

## Genetic Testing

The NIH Genetic Testing Registry (GTR) lists genetic tests available for CYP2C19 (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1557%5Bgeneid%5D), CYP2C9 (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1559%5Bgeneid%5D), CYP3A5 (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1577%5Bgeneid%5D), and CYP2B6 (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1555%5Bgeneid%5D) genes. Since the formation of the active metabolite of prasugrel is not known to be affected by CYP variants, genetic testing before prasugrel use is not recommended.

For clopidogrel, its effectiveness depends on its activation to an active metabolite, primarily by CYP2C19. Therefore, the FDA states that tests identifying an individual’s CYP2C19 genotype can be used as an aid in determining therapeutic strategy.

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA): There is no relevant effect of genetic variation in CYP2B6, CYP2C9, CYP2C19, or CYP3A5 on the pharmacokinetics of prasugrel’s active metabolite or its inhibition of platelet aggregation.

[...]

Prasugrel can be administered with drugs that are inducers or inhibitors of cytochrome P450 enzymes.

Please review the complete therapeutic recommendations that are located here: (1)

## Acknowledgments

The author would like to thank Mohamed Nagy, Clinical Pharmacist, Head of the Personalised Medication Management Unit, Department of Pharmaceutical Services, Children's Cancer Hospital, Cairo, Egypt; Victoria M. Pratt, PhD, FACMG, Director, Pharmacogenomics Laboratory, Department of Medical and Molecular Genetics, Indiana University School of Medicine, Indianapolis, IN, USA; and Stuart A. Scott, Assistant Professor of Genetics and Genomic Sciences, Icahn School of Medicine at Mount Sinai, New York, NY, USA; for reviewing this summary.

## Version History

Version 1.0 of this chapter was published on April 10, 2017.

Version 1.1 of this chapter was published on October 15, 2024. This minor revision features an update to a more recent FDA-approved drug label reference, inclusion of references for international drug package labelling (Canada, Japan). There are no changes to the recommendations or guidelines for genotype-guided dosing of this medication relative to the prior version.

## References

1 PRASUGREL tablet, film coated. East Windsor, NJ, USA: Limited, A.P.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=596c923d-db8d-4b96-bf31-52186a38c30d.
2 Wiviott, S.D., E. Braunwald, C.H. McCabe, G. Montalescot, et al., Prasugrel versus clopidogrel in individuals with acute coronary syndromes. N Engl J Med, 2007. 357(20): p. 2001-15.17982182
3 Wiviott, S.D., E. Braunwald, C.H. McCabe, I. Horvath, et al., Intensive oral antiplatelet therapy for reduction of ischaemic events including stent thrombosis in individuals with acute coronary syndromes treated with percutaneous coronary intervention and stenting in the TRITON-TIMI 38 trial: a subanalysis of a randomised trial. Lancet, 2008. 371(9621): p. 1353-63.18377975
4 Antman, E.M., S.D. Wiviott, S.A. Murphy, J. Voitk, et al., Early and late benefits of prasugrel in individuals with acute coronary syndromes undergoing percutaneous coronary intervention: a TRITON-TIMI 38 (TRial to Assess Improvement in Therapeutic Outcomes by Optimizing Platelet InhibitioN with Prasugrel-Thrombolysis In Myocardial Infarction) analysis. J Am Coll Cardiol, 2008. 51(21): p. 2028-33.18498956
5 Mariani, M., G. Mariani, and S. De Servi, Efficacy and safety of prasugrel compared with clopidogrel in individuals with acute coronary syndromes: results of TRITON-TIMI 38 trials. Expert Rev Cardiovasc Ther, 2009. 7(1): p. 17-23.19105763
6 Wallentin, L., P2Y(12) inhibitors: differences in properties and mechanisms of action and potential consequences for clinical use. Eur Heart J, 2009. 30(16): p. 1964-77.19633016
7 Mallouk, N., C. Labruyere, J.L. Reny, C. Chapelle, et al., Prevalence of poor biological response to clopidogrel: a systematic review. Thromb Haemost, 2012. 107(3): p. 494-506.22273694
8 Brandt, J.T., S.L. Close, S.J. Iturria, C.D. Payne, et al., Common polymorphisms of CYP2C19 and CYP2C9 affect the pharmacokinetic and pharmacodynamic response to clopidogrel but not prasugrel. J Thromb Haemost, 2007. 5(12): p. 2429-36.17900275
9 Mega, J.L., S.L. Close, S.D. Wiviott, L. Shen, et al., Cytochrome P450 genetic polymorphisms and the response to prasugrel: relationship to pharmacokinetic, pharmacodynamic, and clinical outcomes. Circulation, 2009. 119(19): p. 2553-60.19414633
10 Farid, N.A., A. Kurihara, and S.A. Wrighton, Metabolism and disposition of the thienopyridine antiplatelet drugs ticlopidine, clopidogrel, and prasugrel in humans. J Clin Pharmacol, 2010. 50(2): p. 126-42.19948947
11 Ancrenaz, V., Y. Daali, P. Fontana, M. Besson, et al., Impact of genetic polymorphisms and drug-drug interactions on clopidogrel and prasugrel response variability. Curr Drug Metab, 2010. 11(8): p. 667-77.20942779
12 Gurbel, P.A., T.O. Bergmeijer, U.S. Tantry, J.M. ten Berg, et al., The effect of CYP2C19 gene polymorphisms on the pharmacokinetics and pharmacodynamics of prasugrel 5-mg, prasugrel 10-mg and clopidogrel 75-mg in individuals with coronary artery disease. Thromb Haemost, 2014. 112(3): p. 589-97.25008027
13 Franchini, M. and P.M. Mannucci, New antiplatelet agents: why they are needed. Eur J Intern Med, 2009. 20(8): p. 733-8.19892299
14 Jovanovic, L., N. Antonijevic, T. Novakovic, N. Savic, et al., Practical Aspects of Monitoring of Antiplatelet Therapy. Semin Thromb Hemost, 2016.27825182
15 Chan, N.C., J.W. Eikelboom, J.S. Ginsberg, M.N. Lauw, et al., Role of phenotypic and genetic testing in managing clopidogrel therapy. Blood, 2014. 124(5): p. 689-99.24951432
16 Erlinge, D., S. James, S. Duvvuru, J.A. Jakubowski, et al., Clopidogrel metaboliser status based on point-of-care CYP2C19 genetic testing in individuals with coronary artery disease. Thromb Haemost, 2014. 111(5): p. 943-50.24402637
17 Cascorbi, I., O. Bruhn, and A.N. Werk, Challenges in pharmacogenetics. Eur J Clin Pharmacol, 2013. 69 Suppl 1: p. 17-23.23640184
18 Sorich, M.J., A. Vitry, M.B. Ward, J.D. Horowitz, and R.A. McKinnon, Prasugrel vs. clopidogrel for cytochrome P450 2C19-genotyped subgroups: integration of the TRITON-TIMI 38 trial data. J Thromb Haemost, 2010. 8(8): p. 1678-84.20492467
19 Damani, S.B. and E.J. Topol, The case for routine genotyping in dual-antiplatelet therapy. J Am Coll Cardiol, 2010. 56(2): p. 109-11.20471193
20 Lee, J.H., S.G. Ahn, J.W. Lee, Y.J. Youn, et al., Switching from prasugrel to clopidogrel based on Cytochrome P450 2C19 genotyping in East Asian individuals stabilized after acute myocardial infarction. Platelets, 2016. 27(4): p. 301-7.26556524
21 Malhotra, N., J. Abunassar, G.A. Wells, R. McPherson, et al., A pharmacodynamic comparison of a personalized strategy for anti-platelet therapy versus ticagrelor in achieving a therapeutic window. Int J Cardiol, 2015. 197: p. 318-25.26151596
22 Roberts, J.D., G.A. Wells, M.R. Le May, M. Labinaz, et al., Point-of-care genetic testing for personalisation of antiplatelet treatment (RAPID GENE): a prospective, randomised, proof-of-concept trial. Lancet, 2012. 379(9827): p. 1705-11.22464343
23 Jiang, M. and J.H. You, Cost-effectiveness analysis of personalized antiplatelet therapy in individuals with acute coronary syndrome. Pharmacogenomics, 2016. 17(7): p. 701-13.27167099
24 Product Monograph JAMP Prasugrel. Boucherville, Quebec, Canada: Corporation, J.P.; 2020. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=99200.
25 Efient, Prasugrel hydrochloride. Chuo City, Tokyo, Japan: Limited, D.S.C.; 2014. Available from: https://www.pmda.go.jp/english/review-services/reviews/approved-information/drugs/0001.html.

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Brivaracetam Therapy and CYP2C19 Genotype

Carisoprodol Therapy and CYP2C19 Genotype

Celecoxib Therapy and CYP2C9 Genotype

Clobazam Therapy and CYP2C19 Genotype

Clopidogrel Therapy and CYP2C19 Genotype

Clozapine Therapy and CYP Genotype

Diazepam Therapy and CYP2C19 Genotype

Dronabinol Therapy and CYP2C9 Genotype

Esomeprazole Therapy and CYP2C19 Genotype

Flibanserin Therapy and CYP2C19 Genotype

Flurbiprofen Therapy and CYP2C9 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Lacosamide Therapy and CYP2C19 Genotype

Lesinurad Therapy and CYP2C9 Genotype

Omeprazole Therapy and CYP2C19 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Phenytoin Therapy and HLA-B*15:02 and CYP2C9 Genotype

Piroxicam Therapy and CYP2C9 Genotype

Siponimod Therapy and CYP2C9 Genotype

Voriconazole Therapy and CYP2C19 Genotype

Warfarin Therapy and VKORC1 and CYP Genotype

## Tests in GTR by Condition

Prasugrel response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN239061&term=CN239061[DISCUI]&display_string=Prasugrel response)

## Tests in GTR by Gene

CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1557[geneid]+AND+CN239061[cui])

CYP2C9 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1559[geneid]+AND+CN239061[cui])

CYP3A5 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1577[geneid]+AND+CN239061[cui])

CYP2B6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1555[geneid]+AND+CN239061[cui])