# Pegloticase Therapy and G6PD Genotype

## Introduction

Pegloticase (brand name Krystexxa) is used to treat the high levels of uric acid associated with refractory gout. The use of pegloticase is reserved for individuals with symptomatic, chronic gout who have not responded to, or are unable to take, conventional gout treatments. Pegloticase is given once every 2 weeks as an intravenous infusion, and is given in a healthcare setting that is prepared to manage infusion reactions and anaphylaxis (1).

Pegloticase is a pegylated urate oxidase – a modified version of the enzyme that catalyzes the oxidation of uric acid to 5-hydroxyisourate and hydrogen peroxide in most mammalian species. However, urate oxidase is not active in humans due to an inactivating mutation in the gene (2). Subsequent hydrolysis and decarboxylation of 5-hydroxyisourate leads to the formation of a more soluble metabolite (allantoin), which is then excreted by the kidneys.

Red blood cells that lack the glucose-6-phosphate dehydrogenase (G6PD) enzyme are sensitive to oxidative damage caused by agents like hydrogen peroxide. Once exposed, the red blood cells become rigid, trapped, and are rapidly broken down (hemolysis). This can lead to a deficiency of mature red blood cells (hemolytic anemia) and the production of red blood cells with abnormally high levels of methemoglobin (methemoglobinemia).

Approximately 400 million people worldwide have G6PD deficiency. Most of these individuals are asymptomatic. However, they are at risk of life-threating hemolytic reactions and methemoglobinemia if given oxidizing drugs such as pegloticase.

Pegloticase is contraindicated in individuals with G6PD deficiency. The FDA-approved label states that individuals at higher risk for G6PD deficiency should be screened before starting pegloticase therapy, with specific examples including individuals of African, Mediterranean (including Southern European and Middle Eastern), and South Asian ancestry (Table 1) (1). Importantly, approximately 12% of African-Americans have G6PD deficiency.

Table 1.

The FDA Drug Label for Pegloticase. Glucose-6-phosphate dehydrogenase Deficiency Associated Hemolysis and Methemoglobinemia (2020)

Phenotype | Recommendations
G6PD deficiency | Screen individuals at risk for G6PD deficiency before starting pegloticase. For example, individuals of African, Mediterranean (including Southern European and Middle Eastern), and Southern Asian ancestry are at increased risk for G6PD deficiency. Life threatening hemolytic reactions and methemoglobinemia have been reported with pegloticase in individuals with G6PD deficiency. Because of the risk of hemolysis and methemoglobinemia, do not administer pegloticase to individuals with G6PD deficiency.

This table is adapted from (1).

## Drug: Pegloticase

Pegloticase is a urate-lowering drug for adults with severe, chronic refractory gout, which is administered intravenously every 2 weeks. Pegloticase is a member of the drug class of uricases (urate oxidases), which also includes rasburicase. While rasburicase (brand name Elitrek) is licensed for use in managing tumor lysis syndrome, pegloticase is used to treat adults with severe, refractory chronic gout who cannot tolerate or have failed to respond to adequate doses and combinations of available uricostatic or uricosuric urate-lowering drugs.

Gout is one of the most common types of inflammatory arthritis. It affects approximately 4% of adults in the USA and though its global incidence and prevalence are increasing, they have now stabilized in high income Western countries (3-6). Gout is caused by an inflammatory response to urate crystals. Prolonged asymptomatic elevation of serum urate levels (hyperuricemia) above a solubility saturation threshold of approximately 6.8 mg/dL always precedes the development of gout. However, most individuals with hyperuricemia do not develop clinical gouty arthritis, and urate-lowering drugs including pegloticase are not used to treat asymptomatic hyperuricemia.

Patients with gouty arthritis usually present for the first time with an extremely painful acute inflammatory monoarthritis (gout flare) in a lower limb joint such as the first metatarsophalangeal joint in the great toe (podagra), the ankle, or knee. Acute gout flares can occur in the elbows, wrists or small joints of the hands but flares in joints of the upper limbs and acute flares in multiple joints (polyarticular gout) are usually restricted to individuals with longstanding poorly controlled disease. Without treatment, acute gout attacks are self-limiting and will settle in 7–14 days. Following resolution, individuals have a pain-free period of variable length (intercritical gout) before experiencing a further flare. In a few individuals, persistent hyperuricemia is associated with palpable or visible, or both, sub-cutaneous granulomata containing masses of urate crystals known as tophi.

While acute gout flares are treated with anti-inflammatory medications, definitive treatment of gout requires continuous medication with urate-lowering drugs at doses that maintain the serum urate level below that required to prevent urate crystal formation and dissolve existing urate deposits.

There are 3 main types of urate-lowering drugs:

- Uricostatic xanthine oxidase inhibitors that decrease the production of uric acid (for example, allopurinol, febuxostat)
- Uricosuric drugs that inhibit the reabsorption of uric acid in the kidneys (for example, benzbromarone, probenecid, and lesinurad)
- Uricase drugs that convert uric acid to a more soluble metabolite (for example, pegloticase, rasburicase)

Xanthine oxidase inhibitors are the mainstay treatment for gout, with the addition of uricosuric drugs being reserved for individuals who do not have an adequate response.

Despite conventional urate-lowering therapy for gout with uricostatic or uricosuric, or both drugs, a few individuals may continue to have symptomatic, chronic gouty arthritis, with tophi, and high serum uric acid levels. Intravenous infusions of pegloticase can lead to rapid and persistent lowering of urate levels and significant clinical improvement of symptoms in approximately 45% of these individuals (7-9).

Pegloticase is a pegylated urate oxidase –– a modified version of the enzyme that catalyzes the oxidation of uric acid to 5-hydroxyisourate and hydrogen peroxide in most mammalian species, but which is not active in humans. Subsequent hydrolysis and decarboxylation lead to the formation of a more soluble metabolite (allantoin), which is then excreted by the kidneys. Pegloticase is a predominantly porcine-like recombinant uricase, which is modified (“pegylated”) to increase its half-life and to reduce the development of anti-drug protein antibodies. However, clinically significant anti-pegloticase antibodies are detected in approximately 40% of individuals treated with pegloticase, and a high level of antibodies is associated with a higher incidence of infusion reactions (10). However, most of the anti-pegloticase antibodies are directed at the polyethylene glycol component of the drug, rather than the uricase, leading to reduced efficacy as a result of increased drug clearance, and reduction in drug concentration associated with a secondary rise in serum urate levels.

The safety of pegloticase in pregnant women has not been studied, but animal studies showed no evidence of fetal harm. In pregnant rats and rabbits, no fetal structural abnormalities were seen after sub-cutaneous injections of pegloticase during the organogenesis stages of pregnancy.

Gout flares are the most common adverse reactions associated with pegloticase therapy despite flare prophylaxis with colchicine, nonsteroidal anti-inflammatory drugs, or corticosteroids. Infusion reactions and—very rarely—reactions fulfilling criteria for anaphylaxis can occur despite pre-treatment with antihistamines and corticosteroids. Approximately a quarter of individuals experience a mild to moderate infusion reaction with a pruritic urticarial rash, dyspnea, or chest discomfort. More severe anaphylactoid reactions with wheezing, swelling around the mouth and lips, and reduced blood pressure occur in less than 1% of individuals, usually within 2 hours of the infusion. Because of the risk of infusion reactions and anaphylaxis, pegloticase should only be administered in a healthcare setting with monitoring of the individual during the infusion and reducing or stopping treatment if necessary, and subsequently monitoring the individual after the infusion for any signs of anaphylaxis (7, 8, 11). The severity and frequency of these infusion reactions remains an area of debate within the field. The current FDA drug label includes a boxed warning regarding the possibility of anaphylaxis and infusion reactions that could occur during or after pegloticase administration, including the first infusion; thus pegloticase is recommended only for administration in a healthcare setting by providers prepared to manage anaphylaxis and infusion reactions (1, 12).

The use of pegloticase is contraindicated in individuals with G6PD deficiency because of the risk of acute hemolytic anemia and methemoglobinemia (1, 13, 14). This is because a byproduct of the conversion of uric acid to 5-hydroxyisourate is hydrogen peroxide, an oxidizing agent.

Individuals who have G6PD deficiency have red blood cells that are susceptible to oxidative damage. If exposed to agents such as hydrogen peroxide, the red blood cells become rigid, get trapped, and are subsequently destroyed by macrophages in the spleen, bone marrow, and liver. The rapid destruction of red blood cells is called hemolysis, and it may result in hemolytic anemia (a deficiency of red blood cells or hemoglobin, caused by hemolysis).

In addition, hemoglobin may be oxidized to methemoglobin. Hemoglobin binds oxygen and delivers oxygen to the body’s tissues, while methemoglobin does not. Normally, approximately 1% of red blood cells contain methemoglobin. When the levels of methemoglobin increase, red blood cells are less able to delivery oxygen to tissues, resulting in cyanosis (bluish skin color), and potentially life-threatening arrhythmias and seizures (15).

## Gene: G6PD

The G6PD enzyme is encoded by the G6PD gene, which is located on chromosome Xq28. As such, males are hemizygous for one G6PD allele, making them more susceptible to this X-linked disorder. Females randomly inactivate one X chromosome during development, resulting in a mosaic expression of either one X chromosome or the other in their somatic cells. This mosaicism can occur in the hematopoietic progenitor cells that give rise to red blood cells, resulting in mixed expression of G6PD alleles. Females with Turner syndrome (45, X) have only one X chromosome and thus are also hemizygous for the G6PD gene.

Glucose-6-phosphate dehydrogenase deficiency is the most common enzyme deficit in humans, affecting 400 million people worldwide (16), with a worldwide prevalence of approximately 5%. Glucose-6-phosphate dehydrogenase deficiency appears to be protective against malaria infection leading to a higher prevalence (more than 25%) in countries where malaria is, or once was, endemic (for example, tropical Africa, tropical and subtropical Asia, the Middle East, and some parts of the Mediterranean) (17-19). In the US, G6PD deficiency is more common among African-Americans, affecting approximately 12% (20).

The G6PD enzyme catalyzes the first step in the hexose monophosphate shunt (HMP) pathway, which converts glucose to pentose sugars for nucleic acid synthesis. In this step nicotinamide adenine dinucleotide phosphate (NADP+) is reduced to NADPH, which protects cells from oxidative stress. In mature red blood cells, the HMP pathway is the only source of NADPH. This promotes the generation of reduced glutathione that protects the sulfhydryl groups of hemoglobin, which are susceptible to oxidation by hydrogen peroxide and oxygen radicals. Red blood cells that lack G6PD also have a deficiency of NADPH.(21)

Red blood cells that are G6PD and NADPH deficient are more susceptible to oxidative stress by oxygen free radicals and hydrogen peroxide. Oxidative stress occurs naturally, but is increased during illnesses, such as infections and diabetic ketoacidosis. Oxidative stress can also follow the ingestion of fresh fava beans (favism) and is an adverse effect of several drugs (for example, the uric acid lowering drugs pegloticase and rasburicase, the antimalarial drugs primaquine and tafenoquine, the skin cancer drug dabrafenib, and the antibacterials, dapsone and sulfamethoxazole).

Most individuals with G6PD deficiency are asymptomatic –– they have a normal lifespan and may not know they have G6PD deficiency. However, at birth, they are predisposed to neonatal jaundice, and throughout life, they are sensitive to oxidizing agents. All individuals with G6PD deficiency should avoid oxidizing agents when possible, including drugs such as pegloticase.

Symptomatic individuals with G6PD deficiency may suffer from episodes of acute hemolytic anemia, jaundice, and hemoglobinuria or chronic, non-spherocytic, hemolytic anemia. The management of hemolytic episodes depends on the severity of hemolysis, with more severe cases requiring blood transfusions. Folic acid may be given to prevent the worsening of anemia in individuals with folate deficiency and to induce formation of new red blood cells.

More than 180 genetic variants of the G6PD gene have been identified, with approximately 400 biochemical and enzyme variants (22). Most known G6PD variants are missense, which can also be inherited as haplotypes that are comprised of more than one variant allele (23). Large deletions are rare, and a complete lack of G6PD activity is thought to be fatal in utero.

The normal (wild-type) copy of the G6PD gene is known as G6PD B, and is found in most individuals with European, Asian, or African ancestry. Common G6PD variants include:

- G6PD A+ (p.Asn126Asp) has normal enzyme activity and is not associated with hemolysis, and is found in up to 30% of blacks from Africa (24).
- G6PD A- (p.Asn126Asp and p.Val68Met) is associated with mild to moderate hemolysis, and is found in up to 15% of African-Americans (25). Additional A-haplotypes have also been identified, both with the A+ variant with a second single nucleotide polymorphisms (p.Asn126Asp with p.Arg227Leu; and p.Asn126Asp with p.Leu323Pro. See Nomenclature table below for additional information) (26).
- G6PD Mediterranean (p.Ser218Phe) can cause severe hemolysis, and is the most common abnormal variant in Caucasians (27).
- G6PD Canton (p.Arg489Leu) can cause severe hemolysis, and is found in Asians (28).

The World Health Organization categorized G6PD variants into 5 classes according to the level of enzyme activity and severity of hemolysis. Class 1 variants are the most severe, but rare in the general population. These variants have less than 10% of normal GP6D enzyme activity and are associated with chronic hemolytic anemia.

Most individuals with G6PD deficiency have Class II (enzyme activity less than 10% but no chronic hemolytic anemia) or Class III (enzyme activity between 10–60%) variants. Class II and III variants are associated with intermittent hemolysis, usually triggered by infection or drugs, but for most of the time, affected individuals have no symptoms. Class IV and V variants are not considered to be clinically significant, as they are associated with normal (class IV) or increased (class V) enzyme activity (29).

The Clinical Pharmacogenetics Implementation Consortium (CPIC) has assigned G6PD phenotypes based on G6PD genotypes (Table 2) (29).

Table 2.

Assignment of likely G6PD Phenotype based on Genotype/Diplotype (CPIC 2014)

Likely phenotype | Definition | Genotype | Who class for G6PD variants^a^ | Example of diplotype^b^
Normal | Very mild or no enzyme deficiency (less than 60% of normal enzyme levels) | A male who has a non-deficient (class IV) allele | IV | B, Sao Boria
Normal | Very mild or no enzyme deficiency (less than 60% of normal enzyme levels) | A female who has 2 non-deficient (class IV) alleles | IV/IV | B/B, B/Sao Boria
Deficient | Less than 10–60% of normal enzyme activity | A male who has a deficient (class II–III) allele | II, III | A–, Orissa, Kalyan-Kerala, Mediterranean, Canton, Chatham
Deficient | Less than 10–60% of normal enzyme activity | A female who has 2 deficient (class II–III variants) alleles | II/II, II/III, III/III | A–/A–, A–/Orissa, Orissa/Kalyan-Kerala, Mediterranean/Mediterranean, Chatham/ Mediterranean, Canton/Viangchan
Deficient with CNSHA | Severe enzyme deficiency (<10% activity) and associated with CNHSA | A male who has a class I allele | I | Bangkok, Villeurbanne
Deficient with CNSHA | Severe enzyme deficiency (<10% activity) and associated with CNHSA | A female who has 2 deficient (class I variants) alleles | I/I | Bangkok/Bangkok, Bangkok/Villeurbanne
Variable^c^ | Normal or deficient enzyme activity^c^ | A female who has one non-deficient (class IV) and one deficient (class I–III variants) allele | IV/I, IV/II, IV/III | B/A–, B/Mediterranean, B/Bangkok

CNSHA, chronic nonspherocytic hemolytic anemia

WHO, World Health Organization

^a^ WHO classifications (Ref. 14 and Ref. 17, from (29)). Class I variants are extremely rare; the distinction between class II and III variants is not clear, and the “class V” very high activity variant has been reported in only a single case. Therefore, almost all individuals will have class II, III, or IV alleles. It should be noted that the class of a variant may have been assigned only by the clinical manifestations of an individual in which the variant was subsequently identified.

^b^ Due to the large number of G6PD variants, many other diplotypes may be possible besides those given as examples here; see Supplementary Table S1 online for a more comprehensive list of variant alleles with their assigned WHO class (29). For HGVS terms, please see the Nomenclature table below.

^c^ Due to X-linked mosaicism, females heterozygous for one non-deficient (class IV) and one deficient (class I–III variants) allele may display a normal or a deficient phenotype. It is therefore difficult to predict the phenotype of these individuals (Supplementary Material online (G6PD heterozygotes)) (29).

This table is adapted from (29).

## Linking Gene Variation with Treatment Response

Although evidence that directly links G6PD status with an increased risk of hemolytic anemia is limited to case reports of individuals taking pegloticase, it is well established that hydrogen peroxide, which is produced during pegloticase therapy, can cause acute hemolysis in individuals with G6PD deficiency.

The first case of severe hemolysis and methemoglobinemia associated pegloticase therapy was reported in 2014, and a later case of hemolytic anemia was reported in 2016. In both cases, the individuals were later diagnosed to have G6PD deficiency (13-15).

## Genetic Testing

The NIH Genetic Testing Registry, GTR, displays genetic tests that are available for pegloticase response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN575653) and the G6PD (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=2539%5Bgeneid%5D) gene. Molecular genetic testing can be used to confirm the diagnosis of G6PD and may also be used to screen females with a family history of G6PD to see if they are carriers.

Glucose-6-phosphate dehydrogenase deficiency is an X-linked recessive trait and most individuals are asymptomatic throughout life.

X-linked disorders affect males at a much higher rate than females because males only have one copy of the X chromosome (hemizygous, XY). Since females have 2 copies of the X chromosome (XX) they tend to be less affected. However, female carriers can present with a range of phenotypes from no symptoms through a severe deficiency due to the high frequency of G6PD variants. Females randomly inactivate one X chromosome in somatic cells during development, resulting in a mixed population of somatic cells expressing one G6PD allele or the other.

Glucose-6-phosphate dehydrogenase deficiency occurs in homozygous and compound heterozygous females (who have inherited 2 copies of G6PD deficiency alleles) and in heterozygous females (one normal G6PD allele and one deficiency G6PD allele) with skewed X-chromosome inactivation of the functional allele (18). Genetic testing alone is insufficient for heterozygous females with one normal function G6PD allele, as the expression of the 2 alleles will vary between blood cells and over time (29).

A heterozygous mother has a 50% chance of passing G6PD deficiency to a son and a 50% chance of passing the carrier trait to a daughter. Affected fathers pass the variant G6PD to their daughters, but not to their sons (21, 30).

The FDA recommends that individuals at risk of G6PD deficiency be screened for G6PD deficiency before starting pegloticase therapy. However, individuals of all ancestries may be G6PD deficient (worldwide prevalence of 5%). Therefore, caution must be taken in all individuals when initiating pegloticase therapy.

In routine clinical practice, G6PD deficiency is diagnosed by measuring the level of G6PD activity in red blood cells. Two different types of enzyme activity tests are used: qualitative and quantitative. Often, qualitative tests do not accurately detect individuals with intermediate G6PD activity. False results may be obtained immediately after a blood transfusion, because transfused cells are likely to have normal G6PD levels, and immediately after an episode of hemolysis, because young red blood cells have higher levels of G6PD. Therefore, screening for G6PD should be performed 2–3 months after a blood transfusion or hemolytic episode. Of note, G6PD activity false negatives have been reported (14, 21, 29, 31).

In men, if genetic testing determined that an individual was positive for G6PD deficiency, the use of pegloticase would be contraindicated. However, a negative result cannot be entirely relied upon because only a small subset of G6PD variants are routinely tested (21, 29, 30). In addition, G6PD phenotypes may be unpredictable in heterozygous females due to random X-chromosome inactivation.

Universal neonatal screening programs for G6PD deficiency are employed in some countries with a high incidence of G6PD deficiency (more than 3–5% of males) (32). These populations are primarily in Asia, Africa, along the Mediterranean and in the Middle East. Screening either uses quantitative enzyme activity assays, or the fluorescent spot test that visually identifies NADPH, which is produced by G6PD (if the blood spot does not fluoresce, the test is positive for G6PD deficiency) (29).

Relatively inexpensive rapid point of care qualitative tests are used in countries where G6PD deficiency is frequent and can identify individuals with severe G6PD deficiency who would be at risk of severe hemolysis with commencement of antimalarial drug therapy. Unfortunately, however, they are insufficiently sensitive for the detection of individuals with less severe G6PD deficiency in whom pegloticase is also contraindicated. (31)

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2020 Statement from the US Food and Drug Administration (FDA):

Contraindications: Glucose-6-phosphate dehydrogenase (G6PD) deficiency

[...]

Life threatening hemolytic reactions and methemoglobinemia have been reported with pegloticase in patients with glucose-6-phosphate dehydrogenase (G6PD) deficiency. Because of the risk of hemolysis and methemoglobinemia, do not administer pegloticase to patients with G6PD deficiency. Screen patients at risk for G6PD deficiency prior to starting pegloticase. For example, patients of African, Mediterranean (including Southern European and Middle Eastern), and Southern Asian ancestry are at increased risk for G6PD deficiency.

Please review the complete therapeutic recommendations that are located here: (1).

## Nomenclature for Selected G6PD Variants

Common allele name / condition | Alternative names / condition | HGVS reference sequence | | WHO Classification* | dbSNP reference identifier for allele location
Common allele name / condition | Alternative names / condition | Coding | Protein | WHO Classification* | dbSNP reference identifier for allele location
G6PD B | WT | NM_001042351.3 | NP_001035810.1 | IV/ Normal | --
G6PD A+ | p.Asn126Asp | NM_001042351.3 :c.376A>G | NP_001035810.1:p.Asn126Asp | IV/ Normal | rs1050828
G6PD Sao Boria | p.Asp113Asn | NM_001042351.3:c.337G>A | NP_001035810.1:p.Asp113Asn | IV/ Normal | rs5030870
G6PD A- | A-^202A/376G^ | NM_001042351.3 :c.376A>G | NP_001035810.1:p.Asn126Asp | III/ Deficient | rs1050828 rs1050829
G6PD A- | A-^202A/376G^ | NM_001042351.3:c.202G>A | NP_001035810.1:p.Val68Met | III/ Deficient | rs1050828 rs1050829
G6PD A- | A-^680T/376G^ | NM_001042351.3 :c.376A>G | NP_001035810.1:p.Asn126Asp | III/ Deficient | rs1050828 rs137852328
G6PD A- | A-^680T/376G^ | NM_001042351.3: c.680G>T | NP_001035810.1:p.Arg227Leu | III/ Deficient | rs1050828 rs137852328
G6PD A- | A-^968C/376G^ | NM_001042351.3 :c.376A>G | NP_001035810.1:p.Asn126Asp | III/ Deficient | rs1050828 rs76723693
G6PD A- | A-^968C/376G^ | NM_001042351.3:c.968T>C | NP_001035810.1:p.Leu323Pro | III/ Deficient | rs1050828 rs76723693
G6PD Bangkok | p.Lys275Asn | NM_001042351.3:c.202G>A | NP_001035810.1:p.Val68Met | III/ Deficient
G6PD Kalyan-Kerala | p.Glu317Lys | NM_001042351.3:c.949G>A | NP_001035810.1:p.Glu317Lys | III/ Deficient | rs137852339
G6PD Orissa | p.Ala44Gly | NM_001042351.3:c.131C>G | NP_001035810.1:p.Ala44Gly | III/ Deficient | rs78478128
GP6D Canton | p.Arg459Leu | NM_001042351.3: c.1376G>T | NP_001035810.1:p.Arg459Leu | II/ Deficient | rs72554665
G6PD Chatham | p.Ala335Thr | NM_001042351.3:c.1003G>A | NP_001035810.1:p.Ala335Thr | II/ Deficient | rs5030869
G6PD Mediterranean | p.Ser188Phe | NM_001042351.3:c.563C>T | NP_001035810.1:pSer188Phe | II/ Deficient | rs5030868
G6PD Viangchan | p.Val291Met | NM_001042351.3:c.871G>A | NP_001035810.1:p.Val291Met | II/ Deficient | rs137852327
G6PD Villeurbanne | p.Thr334del | NM_001042351.3:c.1000_1002delACC | NP_001035810.1:pThr334del | I/Deficient with CNSHA

Additional allele information available from ClinPGx (https://www.clinpgx.org/gene/PA28469/overview) and CPIC’s G6PD Allele Definition Table (https://api.clinpgx.org/v1/download/file/attachment/G6PD_allele_definition_table.xlsx) (revised 2018).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

* WHO classifications based on (33)

## Acknowledgments

The authors would like to thank Brian F. Mandell MD, PhD, MACP, FACR, Professor, Rheumatic and Immunologic Disease, Vasculitis Care and Research, Cleveland Clinic, Professor and Chairman of Academic Medicine and Editor in Chief, Cleveland Clinic Journal of Medicine, Cleveland, OH, USA; Stuart A. Scott, PhD, FACMG, Professor, Department of Pathology, Stanford University, Palo Alto, CA, Laboratory Director, Stanford Medicine Clinical Genomics Program, Stanford, CA, USA; and George Nuki, Emeritus Professor of Rheumatology at the University of Edinburgh, UK for reviewing this summary.

## References

1 KRYSTEXXA- pegloticase injection, solution [package insert]. Lake Forest, IL: Horizon Therapeutics USA, I.; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=6e566303-d93a-4130-b764-25749829aa95
2 Yeldandi, A.V., X.D. Wang, K. Alvares, S. Kumar, et al., Human urate oxidase gene: cloning and partial sequence analysis reveal a stop codon within the fifth exon. Biochem Biophys Res Commun, 1990. 171(2): p. 641-6.2403354
3 Juraschek, S.P., E.R. Miller, 3rd and A.C. Gelber, Body mass index, obesity, and prevalent gout in the United States in 1988-1994 and 2007-2010. Arthritis Care Res (Hoboken), 2013. 65(1): p. 127-32.22778033
4 Roddy, E. and H.K. Choi, Epidemiology of gout. Rheum Dis Clin North Am, 2014. 40(2): p. 155-75.24703341
5 Smith, E., D. Hoy, M. Cross, T.R. Merriman, et al., The global burden of gout: estimates from the Global Burden of Disease 2010 study. Ann Rheum Dis, 2014. 73(8): p. 1470-6.24590182
6 McGill, N.W., The epidemiology and treatment of gout. Open Access Rheumatol, 2011. 3: p. 73-82.27790006
7 Sundy, J.S., H.S. Baraf, R.A. Yood, N.L. Edwards, et al., Efficacy and tolerability of pegloticase for the treatment of chronic gout in patients refractory to conventional treatment: two randomized controlled trials. JAMA, 2011. 306(7): p. 711-20.21846852
8 UpToDate. Prevention of recurrent gout: Pharmacologic urate-lowering therapy and treatment of tophi [Cited October 29, 2018]. Available from: https://www.uptodate.com/contents/pharmacologic-urate-lowering-therapy-and-treatment-of-tophi-in-patients-with-gout
9 Nuki, G., M. Doherty and P. Richette, Current management of gout: practical messages from 2016 EULAR guidelines. Pol Arch Intern Med, 2017. 127(4): p. 267-277.28430170
10 Guttmann, A., S. Krasnokutsky, M.H. Pillinger and A. Berhanu, Pegloticase in gout treatment - safety issues, latest evidence and clinical considerations. Ther Adv Drug Saf, 2017. 8(12): p. 379-388.29204266
11 Calabrese, L.H., A. Kavanaugh, A.E. Yeo and P.E. Lipsky, Frequency, distribution and immunologic nature of infusion reactions in subjects receiving pegloticase for chronic refractory gout. Arthritis Res Ther, 2017. 19(1): p. 191.28818095
12 Nuki, G. and P. Riches, Changing paradigms in the management of gout. J R Coll Physicians Edinb, 2020. 50(2): p. 124-132.32568281
13 Geraldino-Pardilla, L., D. Sung, J.Z. Xu, M. Shirazi, et al., Methaemoglobinaemia and haemolysis following pegloticase infusion for refractory gout in a patient with a falsely negative glucose-6-phosphate dehydrogenase deficiency result. Rheumatology (Oxford), 2014. 53(12): p. 2310-1.25224415
14 Owens, R.E., H. Swanson and J.D. Twilla, Hemolytic Anemia Induced by Pegloticase Infusion in a Patient With G6PD Deficiency. J Clin Rheumatol, 2016. 22(2): p. 97-8.26906307
15 Roberts, R.L. and L.K. Stamp, Pharmacogenetic considerations in the treatment of gout. Pharmacogenomics, 2015. 16(6): p. 619-29.25876828
16 Ruwende, C., S.C. Khoo, R.W. Snow, S.N. Yates, et al., Natural selection of hemi- and heterozygotes for G6PD deficiency in Africa by resistance to severe malaria. Nature, 1995. 376(6537): p. 246-9.7617034
17 Ruwende, C. and A. Hill, Glucose-6-phosphate dehydrogenase deficiency and malaria. Journal of molecular medicine, 1998. 76(8): p. 581-8.9694435
18 Glucose-6-phosphate dehydrogenase deficiency. WHO Working Group. Bull World Health Organ, 1989. 67(6): p. 601-11.2633878
19 Chinevere, T.D., C.K. Murray, E. Grant, Jr., G.A. Johnson, et al., Prevalence of glucose-6-phosphate dehydrogenase deficiency in U.S. Army personnel. Mil Med, 2006. 171(9): p. 905-7.17036616
20 Kaplan, M., M. Herschel, C. Hammerman, J.D. Hoyer, et al., Hyperbilirubinemia among African American, glucose-6-phosphate dehydrogenase-deficient neonates. Pediatrics, 2004. 114(2): p. e213-9.15286259
21 Cappellini, M.D. and G. Fiorelli, Glucose-6-phosphate dehydrogenase deficiency. Lancet, 2008. 371(9606): p. 64-74.18177777
22 Valencia, S.H., I.D. Ocampo, M.I. Arce-Plata, J. Recht, et al., Glucose-6-phosphate dehydrogenase deficiency prevalence and genetic variants in malaria endemic areas of Colombia. Malar J, 2016. 15(1): p. 291.27225440
23 Miwa, S. and H. Fujii, Molecular basis of erythroenzymopathies associated with hereditary hemolytic anemia: tabulation of mutant enzymes. American journal of hematology, 1996. 51(2): p. 122-32.8579052
24 Boyer, S.H., I.H. Porter and R.G. Weilbacher, Electrophoretic heterogeneity of glucose-6-phosphate dehydrogenase and its relationship to enzyme deficiency in man. Proceedings of the National Academy of Sciences of the United States of America, 1962. 48: p. 1868-76.14014720
25 Reys, L., C. Manso and G. Stamatoyannopoulos, Genetic studies on southeastern Bantu of Mozambique. I. Variants of glucose-6-phosphate dehydrogenase. American journal of human genetics, 1970. 22(2): p. 203-15.5435642
26 McDonagh, E.M., C.F. Thorn, J.M. Bautista, I. Youngster, et al., PharmGKB summary: very important pharmacogene information for G6PD. Pharmacogenet Genomics, 2012. 22(3): p. 219-28.22237549
27 Oppenheim, A., C.L. Jury, D. Rund, T.J. Vulliamy, et al., G6PD Mediterranean accounts for the high prevalence of G6PD deficiency in Kurdish Jews. Human genetics, 1993. 91(3): p. 293-4.8478015
28 McCurdy, P.R., H.N. Kirkman, J.L. Naiman, R.T. Jim, et al., A Chinese variant of glucose-6-phosphate dehydrogenase. The Journal of laboratory and clinical medicine, 1966. 67(3): p. 374-85.4379606
29 Relling, M.V., E.M. McDonagh, T. Chang, K.E. Caudle, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) guidelines for rasburicase therapy in the context of G6PD deficiency genotype. Clin Pharmacol Ther, 2014. 96(2): p. 169-74.24787449
30 Singh, J.A., Lesinurad combination therapy with allopurinol in gout: do CLEAR studies make the treatment of gout clearer? Ann Rheum Dis, 2017. 76(5): p. 779-781.28039184
31 Belfield, K.D. and E.M. Tichy, Review and drug therapy implications of glucose-6-phosphate dehydrogenase deficiency. Am J Health Syst Pharm, 2018. 75(3): p. 97-104.29305344
32 WHO, Guidelines for the treatment of malaria. Third edition. 2015, Geneva, Switzerland: WHO Press. 316.
33 Yoshida, A., E. Beutler and A.G. Motulsky, Human glucose-6-phosphate dehydrogenase variants. Bull World Health Organ, 1971. 45(2): p. 243-53.5316621

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.