# Metoprolol Therapy and CYP2D6 Genotype

## Introduction

Metoprolol is a beta-blocker indicated for the treatment of various cardiovascular diseases, including hypertension, arrhythmias, angina, myocardial infarction, and heart failure (HF). Metoprolol selectively blocks beta_1_-adrenoreceptors, which are expressed predominantly in cardiac tissue. The primary therapeutic effect resulting from the blockade of these receptors is a reduction in heart rate and a decrease in the force of heart contractions.

Metoprolol is metabolized extensively by the hepatic CYP2D6 enzyme. Approximately 8% of Caucasians and 2% of most other populations have absent CYP2D6 activity and are known as “CYP2D6 poor metabolizers (PM).” In addition, several drugs inhibit CYP2D6 activity, such as bupropion, quinidine, fluoxetine, paroxetine, and propafenone.

The FDA-approved drug label for metoprolol states that CYP2D6 PM and normal metabolizers (NM) who concomitantly take drugs that inhibit CYP2D6 will have increased metoprolol blood levels, decreasing metoprolol’s cardioselectivity; co-medication with CYP2D6 inhibitors warrants close monitoring (1). (Table 1) Beta-blockers, such as metoprolol, have been demonstrated in several large clinical trials to be safe and effective for the treatment of individuals with cardiovascular disease. As a mainstay of therapy associated with improvements in quality of life, hospitalization rates, and survival (2, 3), clinical care pathways that might lead to the underutilization of beta-blockers require scrutiny. It is common clinical practice to adjust the dose of metoprolol according to individual heart rate until either the target or maximum tolerated dose is reached. The FDA does not specifically comment on the role of genetic testing for initiating therapy.

The Clinical Pharmacogenetics Implementation Consortium (CPIC) recommends that CYP2D6 PM should initiate metoprolol therapy at the lowest recommended starting dose, and titration should be performed with care and close monitoring for bradycardia. (Table 2) Standard dosing and care are recommended for intermediate metabolizers (IM) and NM of CYP2D6, but no recommendation is made for ultrarapid metabolizers (UM) given the limited data on this phenotype and beta-blocker response. (4)

The Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Pharmacists Association (KNMP) has also published metoprolol dosing recommendations based on CYP2D6 genotype. For individuals who have a CYP2D6 gene variation that reduces the conversion of metoprolol to inactive metabolites (namely, the IM and PM phenotype), DPWG states that the clinical consequences are limited mainly to the occurrence of asymptomatic bradycardia. For CYP2D6 PM or IM, if a gradual reduction in heart rate is desired, or in the event of symptomatic bradycardia, DPWG recommends increasing the dose of metoprolol in smaller steps, prescribing no more than 25% (PM) or 50% (IM) of the standard dose, or both. For CYP2D6 UM, DPWG indicates that clinical response is hardly decreased at a dose of 200 mg/day. However, if efficacy is insufficient at this maximum dose, the DPWG recommends increasing the dose based on effectiveness and side effects up to a maximum of 2.5 times the normal dose, or selecting an alternative. (Table 3) (5).

Table 1:

Statement on CYP2D6-based Interactions with Metoprolol from the Food and Drug Administration (FDA)

Interaction | Effect | Recommendation
CYP2D6 inhibition by other medication(s) | Strong inhibitors of CYP2D6 were shown to double metoprolol concentrations; increases in plasma concentration decrease the cardioselectivity of metoprolol | Monitor individuals closely when the combination cannot be avoided.
CYP2D6 poor metabolizers | Will have increased (several-fold) metoprolol blood levels, decreasing metoprolol’s cardioselectivity. | (None)

Table adapted from (1)

Table 2:

Recommendations from the Clinical Pharmacogenetic Implementation Consortium (CPIC) for Beta-Blocker Therapy by Genotype

CYP2D6 phenotype | Implications^a^ | Recommendation | Classification of recommendation^b^
Ultrarapid metabolizer | Increased metabolism of metoprolol leading to decreased drug concentrations; however, it is unclear whether this results in clinically significant changes in heart rate, blood pressure, or clinical outcomes. | No recommendation for metoprolol therapy due to insufficient evidence regarding diminished metoprolol effectiveness clinically. | No recommendation
Normal metabolizer | Normal metabolism of metoprolol | Initiate standard dosing | Strong
Intermediate metabolizer | Decreased metabolism of metoprolol leading to increased drug concentrations; however, this does not appear to translate into clinically significant changes in heart rate, blood pressure, or clinical outcomes. | Initiate standard dosing | Moderate
Poor metabolizer | Decreased metabolism of metoprolol leading to markedly increased drug concentrations; this leads to greater heart rate and blood pressure reductions. The effect on clinical outcomes is unclear. | Initiate therapy with lowest recommended starting dose. Carefully titrate dose upward to clinical effect or guideline-recommended dose; monitor more closely for bradycardia. Alternatively, consider selecting another beta-blocker. | Moderate
Indeterminate | n/a | No recommendation | No recommendation

n/a, not applicable. Indeterminate: Genotype data for CYP2D6 is either unavailable or cannot be converted to a metabolizer phenotype due to unknown or uncertain allele function.

^a^ Metoprolol has no known active metabolites formed by CYP2D6.

^b^ No recommendation: There is insufficient evidence, confidence, or agreement to provide a recommendation to guide clinical practice. Moderate: There is a close or uncertain balance as to whether the evidence is high quality, and the desirable effects clearly outweigh the undesirable effects. Strong: The evidence is high quality, and the desirable effects clearly outweigh the undesirable effects.

Table adapted from (4).

Table 3:

Recommendations for Metoprolol and CYP2D6 Phenotype from the Dutch Pharmacogenetics Working Group (DPWG)

CYP2D6 phenotype | Effect | Recommendation
UM | Increases the conversion of metoprolol to inactive metabolites. This can increase the dose requirement. However, with a target dose of 200 mg/day, there was no effect on the blood pressure and hardly any effect on the reduction of the heart rate. | Use the maximum dose for the relevant indication as a target dose. If the effectiveness is still insufficient: increase the dose based on effectiveness and side effects to 2.5 times the standard dose or select an alternative. Possible alternatives include: -Heart failure: bisoprolol or carvedilol. -Other indications: atenolol or bisoprolol.
IM | Reduces the conversion of metoprolol to inactive metabolites. However, the clinical consequences are limited mainly to the occurrence of asymptomatic bradycardia | If a gradual reduction in heart rate is desired, or in the event of symptomatic bradycardia: use smaller steps in dose titration, prescribe no more than 50% of the standard dose or both. Other cases: no action required.
PM | Reduces the conversion of metoprolol to inactive metabolites. However, the clinical consequences are limited mainly to the occurrence of asymptomatic bradycardia | If a gradual reduction in heart rate is desired, or in the event of symptomatic bradycardia: use smaller steps in dose titration, prescribe no more than 25% of the standard dose or both. Other cases: no action required.

UM: Ultrarapid metabolizer; IM: Intermediate metabolizer; PM: Poor metabolizer

Table adapted from (5).

## Drug: Metoprolol

Metoprolol is a commonly prescribed drug that belongs to the drug class of beta-adrenoreceptor antagonists, also known as “beta-blockers”. Metoprolol is indicated to treat hypertension, angina, myocardial infarction, and HF (stable, symptomatic [New York Heart Association Class II or III] HF). Metoprolol selectively blocks the beta_1_-adrenoreceptor (1). Beta-blockers are a recommended first-line therapy for cardiac conditions, including various arrhythmias, and as second-line therapy for hypertension by professional medical societies in the US and Europe (6, 7, 8).

There are 2 main types of adrenoreceptors, alpha and beta, each of which has numbered subtypes. The beta adrenoreceptors have 3 subtypes: beta_1_, beta_2_, and beta_3_. All 3 subtypes are coupled to the G_s_ protein, which in turn activates adenylate cyclase, an enzyme that catalyzes the production of cyclic adenosine monophosphate (cAMP) from ATP. The binding of an agonist, such as the catecholamines adrenaline and noradrenaline, to beta receptors leads to a rise in the intracellular concentration of cAMP, which triggers signaling pathways via protein kinase A (9). Stimulation of the beta_1_ receptor, which is predominantly expressed in cardiac tissue, leads to an increase in heart rate and the contractility of the atria and ventricles. It also leads to the increased secretion of hormones from other tissues, including renin (from the kidneys), ghrelin (from the stomach), and amylase (from the salivary glands).

Metoprolol exerts its therapeutic effects by reducing the impact of catecholamine stimulation. Metoprolol reduces heart rate, improves contractile function by stimulating the upregulation of beta_1_ receptors, reduces vasoconstriction, and possibly also reduces the risk of arrhythmias (2, 10, 11, 12). In the treatment of HF, certain beta-blockers, such as extended-release metoprolol succinate, are thought to protect the heart from increased catecholamine stimulation. In the short term, adrenergic activation can help the heart maintain cardiac performance, but over time, continued activation can be detrimental. Harmful effects include a persistently increased heart rate, down-regulation and impaired functioning of the beta receptors, and myocyte hypertrophy and death, which lead to adverse remodeling of heart tissue (10, 13).

Metoprolol is a racemic mixture of R- and S-enantiomers (in equal amounts). S-metoprolol has a higher affinity for the beta_2_ receptors than the R-enantiomer (14). R-metoprolol is predominantly metabolized by O-demethylation, whereas S-metoprolol primarily undergoes alpha-hydroxylation (15, 16, 17). Both pathways are metabolized extensively by CYP2D6, though CYP2D6 seems to metabolize R-metoprolol more efficiently (18). The CYP2D6 enzyme is absent in approximately 8% of Caucasians (PM) and approximately 2% of most other populations. Individuals who lack CYP2D6 activity will have plasma concentrations of metoprolol roughly 5 times higher and may be at an increased risk of side effects (18, 19, 20, 21). Individuals with hepatic or renal failure have also been reported to experience elevated plasma levels of metoprolol and increased exposure (22). Metoprolol has a relatively low (approximately 12%) albumin-bound fraction in plasma, can cross the blood-brain barrier, and shows a dose-related increase in bioavailability, though this increase is not directly proportional (1). At higher plasma concentrations, metoprolol is less cardioselective. Metoprolol can inhibit beta_2_ receptors, which are mainly located in the bronchial and vascular musculature. The FDA-approved drug label advises that individuals with bronchospastic disease should not take beta-blockers, except for individuals who cannot tolerate another antihypertensive treatment; in such cases, the lowest possible dose should be used (1).

In a geriatric population, plasma levels of metoprolol above the median were associated with an increased risk of falls; however, this association was not seen for non-selective beta-blockers (23). The drug label in Canada and the FDA label for metoprolol tartrate recommend lower starting and maintenance doses, as well as safety monitoring in geriatric individuals on metoprolol therapy (24, 25).

The safety and effectiveness of metoprolol have not been established in individuals under 6 years of age, according to the FDA-approved label (1). Metoprolol has not been authorized for pediatric use in Canada (24). Even though beta-blockers are typically not recommended for use in pediatric individuals, off-label use in pediatric heart failure does occur (26). The few studies available provide conflicting outcomes regarding the benefit of beta-blockers in a pediatric HF population. Although this pharmacologic management approach did not appear to cause a significant rate of adverse events, more studies are needed to determine the efficacy of beta-blockers for pediatric HF (26). Much of the use of beta-blockers in a pediatric population is extrapolated from experiences in adults, and CPIC states that their recommendations can, with caution, be extrapolated from adult to pediatric use (4, 27). Changes in gene expression over the lifespan of an individual can impact drug responses; the primary metabolic enzyme for metoprolol, CYP2D6, is absent in fetal development but reaches mature expression within the first several post-natal weeks of life. Less is known regarding the beta-adrenergic receptors (27).

Metoprolol can cross the placenta and is secreted in breast milk (28). There are notable risks to a pregnant mother with untreated hypertension during pregnancy, including pre-eclampsia, gestational diabetes, premature delivery and delivery complications. Likewise, hypertension also increases the risk of adverse fetal outcomes (1). Observational studies have not definitively established nor excluded any drug-associated risk of major congenital malformations during pregnancy for metoprolol tartrate or succinate (1, 25). The combined levels of metoprolol and the alpha-OH-metoprolol metabolite secreted into breast milk are reported to be low (less than 2% of the mother’s weight-adjusted dose), and the amounts ingested by the infant are not expected to cause adverse effects, with studies to date finding no adverse reactions in breastfed infants (29). Changes in gene expression or metabolism can occur during pregnancy; an increase in the clearance rate of metoprolol has been reported during mid and late pregnancy, which may require changes in medication selection or dosing (30). However, the use of metoprolol during pregnancy or nursing is not recommended by Health Canada (24), and the US FDA advises monitoring of a breastfed infant for bradycardia or listlessness (signs of beta-blockade) (1).

## Gene: CYP2D6

The CYP450s are a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are polymorphic and can result in decreased, absent, or increased enzyme activity. One prominent CYP450 member, CYP2D6, is responsible for the metabolism of many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### The CYP2D6 Alleles

The CYP2D6 gene is highly polymorphic, as over 170 star (*) alleles have been described and cataloged at the Pharmacogene Variation (PharmVar) Consortium, and each allele is associated with either normal, decreased, or absent enzyme function (Table 4) (31, 32). Star alleles are defined by the variants detected on one chromosome (haplotype).

The combination of CYP2D6 haplotypes that a person has is used to determine their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele can be assigned an activity score from 0 to 1, which is then used to assign a phenotype (for example, CYP2D6 PM). To promote harmonization, the CPIC and DPWG standardized their CYP2D6 genotype-to-phenotype methods in October 2019, creating a consensus activity scoring guideline. The CYP2D6 phenotype is predicted from the diplotype activity score, defined by the sum of the allele score values, which usually ranges from 0 to 3.0. (33)

- An UM has an activity score greater than 2.25
- A NM phenotype has an activity score of 1.25–2.25
- An IM has an activity score of >0–<1.25
- A PM has an activity score of 0

Table 4.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *27, *33 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6). Activity scores from (34).

The CYP2D6*1 allele is the wild-type allele when no variants are detected and is associated with normal enzyme activity and the NM phenotype. The CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, and *6) (35, 36, 37) or an enzyme with decreased activity (for example, *10, *17, and *41) (32, 38) (see Table 4). There are large inter-ethnic differences in the frequency of these alleles, with *3, *4, *6, and *41 being more common in individuals with European ancestry, *17 more common in those with African ancestry, and *10 more common in individuals with Asian ancestry. (39)

Larger structural variants at the CYP2D6 locus have also been described, including gene duplications, deletions, tandem alleles, gene hybrids (namely, CYP2D6-CYP2D7), and gene conversions. The CYP2D6 gene deletions result in a no-function allele (for example, the *5 allele is a deletion). Duplications have been reported for alleles with both normal and decreased function. For allele duplications, the activity scores for the full complement of CYP2D6 alleles are summed to determine the predicted metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (40).

The frequency of CYP2D6 star alleles with altered function varies across global populations, resulting in different frequencies of the resulting metabolizer phenotypes. Given CYP2D6’s role in the metabolism of many drugs, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency of normal-function star alleles, and thus a high proportion of the population are NMs. However, reduced-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, leading to a higher proportion of IM phenotype individuals in this ancestral group. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, which can correlate with lower metabolizer scores in these individuals. More details regarding published allele and phenotype frequencies are available in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Factors other than genotype can affect CYP2D6 enzyme activity and, thus, the metabolizer phenotype of any individual. Administration of an interacting medication can lead to phenoconversion, whereby an individual with one metabolizer genotype can exhibit the enzymatic activity of a different metabolizer group (higher or lower, depending on the medications). The enzymatic activity of CYP2D6 can be inhibited or reduced by medications, including but not limited to strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, and moderate inhibitors such as duloxetine (24, 41, 42, 43). This can potentially result in NMs or IMs responding to medications as if they were PMs, depending on the strength of the enzyme inhibition. Strong inhibitors can completely inhibit CYP2D6, while moderate inhibitors can reduce activity by 50%. Thus, co-medication with multiple CYP2D6 strong or moderate inhibitors may result in reduced metabolism of drug substrates, as has been observed in psychiatric pharmacotherapy (44, 45 2023). In contrast, discontinuing a concomitant CYP2D6 inhibitor can then revert the individual's CYP2D6 activity back to the genetically predicted baseline phenotype. Coadministration of metoprolol and amiodarone has shown a significant increase in metoprolol concentrations and lower heart rate, despite no significant changes in metoprolol doses (46). The product monograph reviewed by Health Canada for metoprolol states that “strong inhibition of CYP2D6 would result in the change of phenotype into poor metabolizer… caution should therefore be exercised when co-administering potent CYP2D6 inhibitors with metoprolol” (24). The metoprolol tartrate drug labeling approved by the FDA states that strong CYP2D6 inhibitors (such as quinidine, fluoxetine, paroxetine, and propafenone) have been shown to double metoprolol concentrations (25). Integration of CYP2D6 phenoconversion into clinical practice requires knowledge of multiple clinical factors, and tools have been developed to support clinicians (47).

## Other Genes of Interest: ADRB1, ADRB2, OR10P1, SNX9, GRK5

The beta-adrenergic receptors mediate signaling via coupled G-protein signaling. In the heart, beta_1_-adrenergic receptors are the primary target for beta-blockers and represent the major adrenergic receptor (27). Encoded by ADRB1 on chromosome 10q25, the beta_1_-adrenergic receptor is a 7-transmembrane domain protein with intracellular and extracellular portions that facilitate ligand and G-protein binding (48, 49). Binding of a ligand to the receptor induces a conformational change that allows the G-alpha subunit to activate adenylyl cyclase, creating cAMP signaling molecules, which in turn leads to increased intracellular calcium ion levels. Calcium influx drives increased contractility and heart rate, as well as increased electrical automaticity (27).

There are known polymorphisms in ADRB1 that have been associated with disease and altered drug response in some studies. The 2 commonly studied variants are ADRB1 p.Ser49Gly (rs1801252, c.145A>G) and p.Arg389Gly (rs1801253, c.1165G>C). The p.389 residue falls within the G-protein binding intracellular loop, and the p.49 residue occurs in an extracellular loop (27). The C>G single nucleotide polymorphism (SNP) at rs1801253 (p.Arg389Gly) has been reported to occur at a frequency of 27% in individuals of European descent, 40–42% in those of African descent, 32–41% in individuals of Asian descent, and 19–32% in individuals of Latin American descent (50, 51). The variation at p.49 of ADRB1 (c.145A>G, rs1801252) occurs less frequently: 10–12.5% in Asian populations, 13% in European populations, 20–25% in African and African descent populations, and 17–24% in Latin American populations. These 2 variants are in negative linkage disequilibrium, such that it is unlikely for an individual to have a Gly49-Gly389 allele (27). Individuals homozygous for arginine at p.389 have been reported to have an increased risk of hypertension (50), and this variation may interact with other variants in the G-protein signaling pathway to negatively impact survival, particularly in individuals of African ancestry (52).

The beta_2_-adrenergic receptor, encoded by ADRB2 and located on chromosome 5q32, has been associated with nocturnal asthma, obesity, type 2 diabetes, cardiovascular disease, and Parkinson’s disease risk (53). The ADRB2 protein is abundantly expressed in bronchial smooth muscle cells, where activation of the receptor leads to bronchodilation (54). It is also expressed, to a lesser extent, in the cardiac myocytes and vascular smooth muscle cells, contributing to increased heart rate and contractility following adrenergic stimulation (54). There are 2 common variants in ADRB2 that encode amino acid changes: rs1042713 (p.Gly16Arg) and rs1042714 (p.Glu27Gln, c.79G>C), with the minor allele frequencies ranging between 40–50% (54). The Gly16 protein isoform is more susceptible to agonist-stimulated downregulation in vitro (54). The Gln27 variant has been associated with increases in systolic blood pressure and reduced response to isoproterenol (54). A third variant, rs1800888 (p.Thr164Ile), is relatively rare, with a minor allele frequency range of ~1–2% in individuals of European or African ancestry, and it is not detected in Chinese populations (54). This rare allele is associated with reduced response to beta_2_-agonists such as salmeterol or albuterol (54, 55).

A genome-wide association study found that OR10P1 and SNX9-linked variants were associated with changes in heart rate in response to beta-blocker therapy for individuals classified as ‘Black’ in the Pharmacogenomic Evaluation of Antihypertensive Responses (PEAR) and PEAR-2 studies (56). The variants g.56022983T>G (rs17117817, near the olfactory receptor family 10 subfamily-p-member 1 gene OR10P1) or rs2364349 c.1648+912G>A (rs2364349) (linked to the sorting nexin-9 gene SNX9) were associated with a decreased heart rate-lowering response in this population. These loci were found to yield significant association signals in ‘White’ study participants as well (56). There is evidence that OR10P1 is expressed in cardiac tissue and may indirectly interact with ADRB2, though the specific mechanism by which olfactory receptors impact heart rate is unknown. Sorting nexin-9 is associated with endocytosis of transmembrane signaling proteins and may be involved in regulating the endocytosis of ADRB2.

One study also found a connection between GRK5 variation and improved survival in HF. p.Gln41Leu (c.122A>T) in the G-protein-coupled receptor kinase 5 protein (rs17098707, now rs2230345) was reported to be more common in individuals of African ancestry than in Caucasians and may attenuate beta-adrenergic signaling, similar to beta-blocker medication (57). This same allele was examined in a Chinese population with an allele frequency of 0.008, but it was not associated with differences in systolic HF mortality compared with the reference allele (58).

## Linking CYP2D6 and ADRB1/2 Genetic Variation with Treatment Response

Genetic variants of the CYP2D6 gene have been found to influence the ratio of enantiomers, the dose and dose titration of metoprolol, and heart rate—CYP2D6 PM have an increased risk of bradycardia (59, 60, 61, 62, 63, 64). However, in one study, CYP2D6 did not appear to influence the efficacy of metoprolol when used to treat hypertension (65). Reduced function of CYP2D6 enzyme alters the pharmacokinetics of metoprolol, resulting in increased exposure (measured by plasma area under the concentration-time curve levels) in PMs and IMs (*10/*10) and this is correlated with a higher risk of bradycardia in PMs (66). In a genome-wide association biobank study using ‘white’ (self-reported) study participants, metoprolol and alpha-OH-metoprolol concentrations were significantly associated with genetic variation located only in the CYP2D6 locus (67).

A meta-analysis of 21 studies reported a significant difference in the BP-lowering effects of metoprolol between CYP2D6 PMs and all other phenotypes (68). At similar doses, individuals with a PM CYP2D6 phenotype experienced a larger decrease in heart rate (measured in beats per minute, BPM), blood pressure (both systolic and diastolic), and more cases of bradycardia (heart rate of less than 60 BPM) across the relevant studies (68).

Variants within the beta_1_ receptor have also been found to influence the treatment response to specific beta-blockers. The most studied is a reduced-function variant, p.Gly389Arg (rs1801253), which leads to reduced levels of cAMP and diminished beta_1_ receptor signaling cascades (69). Individuals who are homozygous p.Arg389 may have a more favorable response to metoprolol treatment than individuals who are homozygous for the reference sequence p.Gly389 (69, 70, 71, 72, 73). The p.Ser49Gly (rs1801252) variant has been reported to be associated with increased ventricular ectopic beats and favorable beta-blocker response in a cohort study of hypertrophic cardiomyopathy (HCM), though the p.Gly389Arg polymorphism did not show significant impacts on beta-blocker response in this HCM cohort (74). The ADRB1 p.Gly389Arg (rs1801253) variant, which was associated with decreased response to beta-blockers, was detected in roughly half the cohort from the Alabama Genomic Health Initiative that had a prescription for one of the affected medicines, including metoprolol (75). One study found that individuals with HF and a variant allele (p.389Arg) at rs1801253 benefited from higher doses of beta-blockers (76). In a separate study, p.389Arg homozygous individuals had greater improvement in left ventricular ejection fraction compared with individuals with the homozygous reference allele (77). However, the CPIC guideline writing committee found the data insufficient to issue recommendations regarding genetic variations in ADRB1 and beta-blocker therapy, citing a need for additional research to refute or confirm the reported findings to date (4).

Additional studies have examined the role of beta_2_ receptor variants and heart rate responses to beta-blockers (78). The PEAR-2 trial examined variants in metoprolol response for individuals with hypertension, finding a significant association of a more pronounced heart rate-lowering response with ADRB2 rs1042714 C/C genotype (encoding Gln at p.27) and a “trending toward significant” association with rs1042713 A-allele in ADRB2 (78). In contrast, the p.27Glu genotype was associated with longer survival for individuals with HF who were taking beta-blockers, and no association was observed with the p.Arg16Gly variants and clinical outcomes (76). This literature was also insufficient to justify clinical recommendations from the CPIC writing committee for beta-blockers and ADRB2 variation (4).

Other studies have failed to find associations between ADRB1 or ADRB2 common variants and blood pressure responses to beta-blockers (79), though it is unclear if the underlying cardiac disorder may impact the specific drug response (or lack of response) associated with genetic variants.

## Genetic Testing

The NIH’s Genetic Testing Registry provides examples of the genetic tests available for metoprolol response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN077996) and the CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5Bgeneid%5D).

The available CYP2D6 tests include targeted single-gene tests as well as multi-gene panels. In addition, variant CYP2D6 alleles to be included in clinical genotyping assays have been recommended by the Association for Molecular Pathology (AMP) (80). For CYP2D6, the AMP recommends that the minimum panel of variant alleles should include *2, *3, *4, *5, *6, *9, *10, *17, *29, *41, and a copy number interrogation. Results are reported as a diplotype, such as CYP2D6 *1/*1; however, copy number testing is crucial when interpreting CYP2D6 results (81). When individuals have more than 2 copies of CYP2D6, the copies of the allele are denoted by an “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6 *1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use the notation of duplication (“DUP”) to indicate an increase in copy number, but the report does not always specify the number of duplications or the allele that has been duplicated due to technical limitations. The test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be confirmed by checking the diplotype and calculating the CYP2D6 activity score, as described in the “CYP2D6 Alleles” section above.

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in real-world clinical settings (82, 83, 84). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, where gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (85).

## The CYP2D6 Gene Interactions with Medications Used for Additional Indications

The CYP family of enzymes is involved in the metabolism of many substances, and CYP2D6 has been implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

● Antipsychotics—for example, aripiprazole, risperidone, and thioridazine[underlined: ,] and to a lesser extent, clozapine[underlined: ,] are metabolized by CYP2D6. According to the FDA, aripiprazole dosage should be reduced for PMs, and thioridazine is contraindicated for individuals known to have reduced CYP2D6 activity due to an increased risk of potentially fatal side effects. The UMs may have a decreased plasma concentration of risperidone.

● Tricyclic antidepressants—for example, amitriptyline and imipramine may require dosage adjustments, potentially guided by therapeutic drug monitoring, to achieve the desired therapeutic range in UMs or PMs. Ultimately, tricyclic antidepressants may be ineffective in CYP2D6 UMs.

● Serotonin and norepinephrine reuptake inhibitors, for example atomoxetine and venlafaxine may have reduced efficacy in UMs at standard doses, while PMs are at risk of elevated plasma concentrations for both medications. The DPWG advises against the use of venlafaxine in CYP2D6 PMs and IMs.

● Antimalarial medications—for example, primaquine is activated by CYP2D6 and CYP450 Nicotinamide Adenine Dinucleotide Phosphate oxidoreductase.

● Anticancer medications—for example, tamoxifen is activated by CYP2D6, and IMs or PMs may have reduced benefit from tamoxifen therapy.

● Pain management—for example, codeine and tramadol are pro-drugs that require activation by CYP2D6 to achieve the desired analgesic effect.

● Various therapies for genetic disorders, for example, eliglustat used in the treatment of Gaucher disease, and deutetrabenazine, used in the treatment of Huntington disease, have reduced dose recommendations for CYP2D6 PMs. The CYP2D6 UMs may not achieve adequate concentrations of eliglustat, and therefore CYP2D6 genotyping is required before initiating eliglustat therapy.

It is important to note that CYP2D6 is the most common biomarker in drug responses for FDA drug labels. The lists provided here is by no means exhaustive. Additional information on gene-drug interactions for CYP2D6 is available from ClinPGx (https://www.clinpgx.org/gene/PA128), CPIC (https://cpicpgx.org/genes-drugs/), and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA):

CYP2D6 Inhibitors are likely to increase metoprolol concentration. […] Drugs that are strong inhibitors of CYP2D6 such as quinidine, fluoxetine, paroxetine, and propafenone were shown to double metoprolol concentrations. While there is no information about moderate or weak inhibitors, these too are likely to increase metoprolol concentration. Increases in plasma concentration decrease the cardioselectivity of metoprolol … Monitor patients closely when the combination cannot be avoided.

[…]

Drug Interactions

CYP2D6

Metoprolol is metabolized predominantly by CYP2D6. In healthy subjects with CYP2D6 extensive metabolizer phenotype, coadministration of quinidine 100 mg, a potent CYP2D6 inhibitor, and immediate-release metoprolol 200 mg tripled the concentration of S-metoprolol and doubled the metoprolol elimination half-life.

[…]

CYP2D6 is absent in about 8% of Caucasians (poor metabolizers) and about 2% of most other populations. CYP2D6 can be inhibited by several drugs. Poor metabolizers of CYP2D6 will have increased (several-fold) metoprolol blood levels, decreasing metoprolol's cardioselectivity.

Please review the complete therapeutic recommendations that are located here: (1)

2024 Summary of recommendations from the Clinical Pharmacogenetics Implementation Consortium (CPIC):

The evidence supporting the association of CYP2D6 genotype with metoprolol exposure and response included participants with a variety of health statuses (e.g., healthy, hypertension, heart failure, etc.). Therefore, it may be reasonable to assume that the pharmacokinetic effects of CYP2D6 variation would affect clinical metoprolol response similarly across a variety of indications, and the dosing recommendations provided could be utilized for most cardiovascular indications …

Recommendations primarily focus on minimizing the risk of adverse effects in CYP2D6 poor metabolizers related to the greater observed reductions in heart rate and blood pressure stemming from increased metoprolol systemic exposure. In addition, the maximally tolerated metoprolol dose may be lower in poor metabolizers compared with normal metabolizers due to these pharmacokinetic differences… We found insufficient evidence to support recommendations related to CYP2D6 genotype and other clinical outcomes.

While the evidence suggests metoprolol plasma concentrations are also increased in CYP2D6 intermediate metabolizers compared with normal metabolizers, these effects appear smaller in magnitude than those observed with poor metabolizers, and there was insufficient evidence to clarify whether these smaller pharmacokinetic differences significantly affect clinical response.

… Most of the data available regarding associations between CYP2D6 genotype and metoprolol response are related to oral formulations; limited evidence exists regarding pharmacogenetic effects with intravenous formulations.

….

CYP2D6 normal and intermediate metabolizers: Recommendations: Initiate standard dosing.

CYP2D6 poor metabolizers: Recommendations: Initiate therapy with lowest recommended starting dose. Carefully titrate dose upward to clinical effect or guideline-recommended dose; monitor more closely for bradycardia. Alternatively, consider selecting another beta-blocker.

CYP2D6 ultrarapid metabolizers: No recommendation for metoprolol therapy due to insufficient evidence regarding diminished metoprolol effectiveness clinically.

Please review the complete therapeutic recommendations that are located here: (4)

2022 Summary of recommendations from the Pharmacogenetics Working Group of the Royal Dutch Association for the Advancement of Pharmacy (KNMP):

CYP2D6 Poor Metabolizers:

The gene variation reduces the conversion of metoprolol to inactive metabolites. However, the clinical consequences are limited mainly to the occurrence of asymptomatic bradycardia.

Recommendation:

If a gradual reduction in heart rate is desired, or in the event of symptomatic bradycardia:

1. Use smaller steps in dose titration and/or prescribe no more than 25% of the standard dose

Other cases:

1 No action required

CYP2D6 Intermediate Metabolizers:

The gene variation reduces the conversion of metoprolol to inactive metabolites. However, the clinical consequences are limited mainly to the occurrence of asymptomatic bradycardia.

Recommendation:

If a gradual reduction in heart rate is desired, or in the event of symptomatic bradycardia:

1. Use smaller steps in dose titration and/or prescribe no more than 50% of the standard dose.

Other cases:

1. No action required

CYP2D6 Ultrarapid Metabolizers:

The gene variation increases the conversion of metoprolol to inactive metabolites. This can increase the dose requirement. However, with a target dose of 200 mg/day, there was no effect on the blood pressure and hardly any effect on the reduction of the heart rate.

Recommendation:

1. Use the maximum dose for the relevant indication as a target dose

2. If the effectiveness is still insufficient: increase the dose based on effectiveness and side effects to 2.5 times the standard dose or select an alternative

Possible alternatives include:

- Heart failure: bisoprolol or carvedilol. Bisoprolol: advantage: not metabolised by CYP2D6; disadvantage: elimination depends on the kidney function. Carvedilol: advantage: elimination does not depend on the kidney function; disadvantage: is metabolised (to a lesser extent than metoprolol) by CYP2D6.
- Other indications: atenolol or bisoprolol. Neither is metabolised by CYP2D6.

Please review the complete therapeutic recommendations that are located here: (5)

## Nomenclature of Selected CYP2D6 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A+1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (80)

^[2]^ AMP Tier 2 allele, (80)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (86).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (28).

## Nomenclature of Selected ADRB1 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
Ser49Gly | ADRB1 Ser49Gly | NM_000684.3:c.145A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/17747/) | NP_000675.1:p.Ser49Gly | rs1801252 (https://www.ncbi.nlm.nih.gov/snp/rs1801252)
Arg389Gly | ADRB1 Arg389Gly | NM_000684.3:c.1165G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/17746) | NP_000675.1:p.Gly389Arg | rs1801253 (https://www.ncbi.nlm.nih.gov/snp/rs1801253)

## Nomenclature of Selected ADRB2 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
Gly16Arg | ADRB2 Gly16Arg | NM_000024.6:c.46G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/225937/) | NP_000015.2:p.Gly16Arg (https://www.ncbi.nlm.nih.gov/clinvar/variation/225937/) | rs1042713 (https://www.ncbi.nlm.nih.gov/snp/rs1042713)
Glu27Gln | ADRB2 Glu27Gln | NM_000024.6:c.79G>C | NP_000015.2:p.Glu27Gln | rs1042714 (https://www.ncbi.nlm.nih.gov/snp/rs1042714)

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (86).

## Acknowledgments

2024 Edition: (v2.0)

The author would like to thank Jordan Baye, PharmD, MA, BCPS, Associate Professor, College of Pharmacy and Allied Health Professions, South Dakota State University, Sioux Falls, SD, USA; Maxime Meloche-Brouillette, PhD, Research Associate, Montreal Heart Institute, and Faculty of Pharmacy, Université de Montréal, Montreal, QC, Canada; Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; and Mollie M. Walton, MD, Pediatric Cardiologist and Clinical Pharmacology Fellow, Pediatric Cardiology, Children’s Mercy, Kansas City, MO, USA for reviewing this summary.

2017 Edition (Published April 4, 2017, v1.0):

The author would like to thank Larisa H. Cavallari, PharmD, Associate Professor, Department of Pharmacotherapy and Translational Research & Director, Center for Pharmacogenomics, University of Florida, Gainesville, FL, USA; Mandy van Rhenen, secretary of the Dutch Pharmacogenetics Working Group (DPWG), Centre for Information on Medicines, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; and John Wikstrand, Professor of Clinical Physiology, Wallenberg Laboratory, University of Gothenburg, Sweden, for reviewing this summary.

## Version History

The April 4, 2017 version (1.0) of this chapter is available as a PDF here.

Version 2.0 published on September 19, 2024 encompasses new recommendations from CPIC that were not previously available as well as expanded recommendations from DPWG that include dosing adjustment guidelines for CYP2D6 IM and UM individuals. Language from the FDA-approved drug label discussing drug-drug interactions via CYP metabolism is also included in version 2.0. Updated CYP2D6 allele information, activity scores and translation from genotype-based activity scores to predicted metabolizer phenotype are also provided in this version based on harmonized international standards. The Genetic Testing section also includes the recommendations from AMP regarding Tier 1 and Tier 2 alleles for CYP2D6 pharmacogenetic testing.

A minor revision (version 2.1) was published on January 17, 2025 to address formatting issues and updated the CYP2D6 Allele Nomenclature table to reflect the AMP Tier 1 and Tier 2 allele designations as well as additional references in the footnotes.

A minor revision (version 2.2) was published on July 27, 2026 to correct resource links to ClinPGx (previously PharmGKB).

## References

1 Metoprolol succinate Piscataway, NJ, USA: Camber Pharmaceuticals Inc.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=74a28333-53c1-493e-b6ad-2192fdc35391.
2 Effect of metoprolol CR/XL in chronic heart failure: Metoprolol CR/XL Randomised Intervention Trial in Congestive Heart Failure (MERIT-HF). Lancet, 1999. 353(9169): p. 2001–7.10376614
3 Kotecha, D., L. Manzano, H. Krum, G. Rosano, et al., Effect of age and sex on efficacy and tolerability of beta blockers in patients with heart failure with reduced ejection fraction: individual patient data meta-analysis. BMJ, 2016. 353: p. i1855.27098105
4 Duarte, J.D., C.D. Thomas, C.R. Lee, R. Huddart, et al., Clinical Pharmacogenetics Implementation Consortium Guideline (CPIC) for CYP2D6, ADRB1, ADRB2, ADRA2C, GRK4, and GRK5 Genotypes and Beta-Blocker Therapy. Clin Pharmacol Ther, 2024.
5 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. Metoprolol – CYP2D6 [Cited May 2024]. Available from https://www.knmp.nl/dossiers/farmacogenetica.
6 Whelton, P.K., R.M. Carey, W.S. Aronow, D.E. Casey, Jr., et al., 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension, 2018. 71(6): p. e13–e115.29133356
7 Williams, B., G. Mancia, W. Spiering, E. Agabiti Rosei, et al., 2018 ESC/ESH Guidelines for the management of arterial hypertension: The Task Force for the management of arterial hypertension of the European Society of Cardiology and the European Society of Hypertension: The Task Force for the management of arterial hypertension of the European Society of Cardiology and the European Society of Hypertension. J Hypertens, 2018. 36(10): p. 1953–2041.30234752
8 Mancia, G., S.E. Kjeldsen, R. Kreutz, A. Pathak, et al., Individualized Beta-Blocker Treatment for High Blood Pressure Dictated by Medical Comorbidities: Indications Beyond the 2018 European Society of Cardiology/European Society of Hypertension Guidelines. Hypertension, 2022. 79(6): p. 1153–1166.35378981
9 Whirl-Carrillo, M., R. Huddart, L. Gong, K. Sangkuhl, et al., An Evidence-Based Framework for Evaluating Pharmacogenomics Knowledge for Personalized Medicine. Clin Pharmacol Ther, 2021. 110(3): p. 563–572.34216021
10 Bristow, M.R., beta-adrenergic receptor blockade in chronic heart failure. Circulation, 2000. 101(5): p. 558–69.10662755
11 Yoshikawa, T., S. Handa, T. Anzai, H. Nishimura, et al., Early reduction of neurohumoral factors plays a key role in mediating the efficacy of beta-blocker therapy for congestive heart failure. Am Heart J, 1996. 131(2): p. 329–36.8579029
12 Gilbert, E.M., W.T. Abraham, S. Olsen, B. Hattler, et al., Comparative hemodynamic, left ventricular functional, and antiadrenergic effects of chronic treatment with metoprolol versus carvedilol in the failing heart. Circulation, 1996. 94(11): p. 2817–25.8941107
13 Sackner-Bernstein, J.D. and D.M. Mancini, Rationale for treatment of patients with chronic heart failure with adrenergic blockade. JAMA, 1995. 274(18): p. 1462–7.7474194
14 Cerqueira, P.M., E.J. Cesarino, F.H. Mateus, Y. Mere, Jr., et al., Enantioselectivity in the steady-state pharmacokinetics of metoprolol in hypertensive patients. Chirality, 1999. 11(7): p. 591–7.10423287
15 Murthy, S.S., H.U. Shetty, W.L. Nelson, P.R. Jackson, et al., Enantioselective and diastereoselective aspects of the oxidative metabolism of metoprolol. Biochem Pharmacol, 1990. 40(7): p. 1637–44.2222517
16 Antunes Nde, J., R.C. Cavalli, M.P. Marques, E.C. Moises, et al., Influence of gestational diabetes on the stereoselective pharmacokinetics and placental distribution of metoprolol and its metabolites in parturients. Br J Clin Pharmacol, 2015. 79(4): p. 605–16.25291152
17 Borg, K.O., E. Carlsson, K.J. Hoffmann, T.E. Jonsson, et al., Metabolism of metoprolol-(3-h) in man, the dog and the rat. Acta Pharmacol Toxicol (Copenh), 1975. 36(Suppl 5): p. 125–35.1079685
18 Blake, C.M., E.D. Kharasch, M. Schwab, and P. Nagele, A meta-analysis of CYP2D6 metabolizer phenotype and metoprolol pharmacokinetics. Clin Pharmacol Ther, 2013. 94(3): p. 394–9.23665868
19 Rau, T., H. Wuttke, L.M. Michels, U. Werner, et al., Impact of the CYP2D6 genotype on the clinical effects of metoprolol: a prospective longitudinal study. Clin Pharmacol Ther, 2009. 85(3): p. 269–72.19037197
20 Jin, S.K., H.J. Chung, M.W. Chung, J.I. Kim, et al., Influence of CYP2D6*10 on the pharmacokinetics of metoprolol in healthy Korean volunteers. J Clin Pharm Ther, 2008. 33(5): p. 567–73.18834373
21 Wuttke, H., T. Rau, R. Heide, K. Bergmann, et al., Increased frequency of cytochrome P450 2D6 poor metabolizers among patients with metoprolol-associated adverse effects. Clin Pharmacol Ther, 2002. 72(4): p. 429–37.12386645
22 Zamir, A., I. Hussain, A. Ur Rehman, W. Ashraf, et al., Clinical Pharmacokinetics of Metoprolol: A Systematic Review. Clin Pharmacokinet, 2022. 61(8): p. 1095–1114.35764772
23 Ploegmakers, K.J., E.P. van Poelgeest, L.J. Seppala, S.C. van Dijk, et al., The role of plasma concentrations and drug characteristics of beta-blockers in fall risk of older persons. Pharmacol Res Perspect, 2023. 11(6): p. e01126.37885367
24 PRODUCT MONOGRAPH INCLUDING PATIENT MEDICATION INFORMATION, AA-METOPROLOL SR. Vaughan, Ontario, Canada: AA Pharma Inc.; 2022. Available from: https://pdf.hres.ca/dpd_pm/00067786.PDF.
25 METOPROLOL TARTRATE- metoprolol tablet. Inc., A.P.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=24837d82-0f3f-4482-9af0-31e5f675c30f.
26 Alabed, S., A. Sabouni, S. Al Dakhoul, and Y. Bdaiwi, Beta-blockers for congestive heart failure in children. Cochrane Database Syst Rev, 2020. 7(7): p. CD007037.32700759
27 Walton, M. and J.B. Wagner, Pediatric Beta Blocker Therapy: A Comprehensive Review of Development and Genetic Variation to Guide Precision-Based Therapy in Children, Adolescents, and Young Adults. Genes (Basel), 2024. 15(3).
28 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, et al., Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542–545.34091888
29 Metoprolol, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000215.
30 Ryu, R.J., S. Eyal, T.R. Easterling, S.N. Caritis, et al., Pharmacokinetics of metoprolol during pregnancy and lactation. J Clin Pharmacol, 2016. 56(5): p. 581–9.26461463
31 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154–170.31544239
32 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399–401.29134625
33 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215–223.27441996
34 CYP2D6 allele functionality table [Cited 6 June 2024]. Available from https://api.clinpgx.org/v1/download/file/attachment/CYP2D6_allele_functionality_reference.xlsx.
35 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256–63.8287064
36 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6–13.15492763
37 ClinPGx [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*4 [Cited 26 Sept 2016]. Available from https://www.clinpgx.org/haplotype/PA165816579.
38 ClinPGx [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 26 Sept 2016]. Available from https://www.clinpgx.org/haplotype/PA165816582.
39 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229–43.11972444
40 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
41 US FDA. Drug Development and Drug Interactions | Table of Substrates, Inhibitors and Inducers. 2023 5 June 2023 7 June 2024]; Available from: https://www.fda.gov/drugs/drug-interactions-labeling/drug-development-and-drug-interactions-table-substrates-inhibitors-and-inducers.
42 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842–1850.30670877
43 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933–939.29882961
44 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024.
45 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
46 Robert, S., M.O. Pilon, E. Oussaid, M. Meloche, et al., Impact of amiodarone use on metoprolol concentrations, alpha-OH-metoprolol concentrations, metoprolol dosing and heart rate: A cross-sectional study. Pharmacol Res Perspect, 2023. 11(5): p. e01137.37732835
47 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677–687.34231197
48 Yang-Feng, T.L., F.Y. Xue, W.W. Zhong, S. Cotecchia, et al., Chromosomal organization of adrenergic receptor genes. Proc Natl Acad Sci U S A, 1990. 87(4): p. 1516–20.2154750
49 Frielle, T., S. Collins, K.W. Daniel, M.G. Caron, et al., Cloning of the cDNA for the human beta 1-adrenergic receptor. Proc Natl Acad Sci U S A, 1987. 84(22): p. 7920–4.2825170
50 Dorn, G.W., 2nd, Adrenergic signaling polymorphisms and their impact on cardiovascular disease. Physiol Rev, 2010. 90(3): p. 1013–62.20664078
51 Reference SNP (rs) Report rs1801253 [Cited 2024]. Available from https://www.ncbi.nlm.nih.gov/snp/rs1801253.
52 Johnson, A.E., K. Hanley-Yanez, C.W. Yancy, A.L. Taylor, et al., Adrenergic Polymorphisms and Survival in African Americans With Heart Failure: Results From A-HeFT. J Card Fail, 2019. 25(7): p. 553–560.30978507
53 ADRB2 adrenoreceport beta 2 [Homo sapiens (human)]. Gene 2 May 2024 [cited 2024; Available from: https://www.ncbi.nlm.nih.gov/gene/154.
54 Litonjua, A.A., L. Gong, Q.L. Duan, J. Shin, et al., Very important pharmacogene summary ADRB2. Pharmacogenet Genomics, 2010. 20(1): p. 64–9.19927042
55 Leineweber, K. and G. Heusch, Beta 1- and beta 2-adrenoceptor polymorphisms and cardiovascular diseases. Br J Pharmacol, 2009. 158(1): p. 61–9.19422376
56 Shahin, M.H., D.J. Conrado, D. Gonzalez, Y. Gong, et al., Genome-Wide Association Approach Identified Novel Genetic Predictors of Heart Rate Response to beta-Blockers. J Am Heart Assoc, 2018. 7(5).
57 Liggett, S.B., S. Cresci, R.J. Kelly, F.M. Syed, et al., A GRK5 polymorphism that inhibits beta-adrenergic receptor signaling is protective in heart failure. Nat Med, 2008. 14(5): p. 510–7.18425130
58 Kang, S., X. Hong, C.W. Ruan, P. Yu, et al., Effects of GRK5 and ADRB1 polymorphisms influence on systolic heart failure. J Transl Med, 2015. 13: p. 44.25638254
59 Baudhuin, L.M., W.L. Miller, L. Train, S. Bryant, et al., Relation of ADRB1, CYP2D6, and UGT1A1 polymorphisms with dose of, and response to, carvedilol or metoprolol therapy in patients with chronic heart failure. Am J Cardiol, 2010. 106(3): p. 402–8.20643254
60 Batty, J.A., A.S. Hall, H.L. White, J. Wikstrand, et al., An investigation of CYP2D6 genotype and response to metoprolol CR/XL during dose titration in patients with heart failure: a MERIT-HF substudy. Clin Pharmacol Ther, 2014. 95(3): p. 321–30.24193112
61 Hamadeh, I.S., T.Y. Langaee, R. Dwivedi, S. Garcia, et al., Impact of CYP2D6 polymorphisms on clinical efficacy and tolerability of metoprolol tartrate. Clin Pharmacol Ther, 2014. 96(2): p. 175–81.24637943
62 Bijl, M.J., L.E. Visser, R.H. van Schaik, J.A. Kors, et al., Genetic variation in the CYP2D6 gene is associated with a lower heart rate and blood pressure in beta-blocker users. Clin Pharmacol Ther, 2009. 85(1): p. 45–50.18784654
63 Collett, S., A. Massmann, N.J. Petry, J. Van Heukelom, et al., Metoprolol and CYP2D6: A Retrospective Cohort Study Evaluating Genotype-Based Outcomes. J Pers Med, 2023. 13(3).
64 Huang, J., S.K. Chuang, C.L. Cheng, and M.L. Lai, Pharmacokinetics of metoprolol enantiomers in Chinese subjects of major CYP2D6 genotypes. Clin Pharmacol Ther, 1999. 65(4): p. 402–7.10223777
65 Zineh, I., A.L. Beitelshees, A. Gaedigk, J.R. Walker, et al., Pharmacokinetics and CYP2D6 genotypes do not predict metoprolol adverse events or efficacy in hypertension. Clin Pharmacol Ther, 2004. 76(6): p. 536–44.15592325
66 Lee, C.M., P. Kang, C.K. Cho, H.J. Park, et al., Physiologically based pharmacokinetic modelling to predict the pharmacokinetics of metoprolol in different CYP2D6 genotypes. Arch Pharm Res, 2022. 45(6): p. 433–445.35763157
67 Laverdiere, J., M. Meloche, S. Provost, G. Leclair, et al., Pharmacogenomic markers of metoprolol and alpha-OH-metoprolol concentrations: a genome-wide association study. Pharmacogenomics, 2023. 24(8): p. 441–448.37307170
68 Meloche, M., M. Khazaka, I. Kassem, A. Barhdadi, et al., CYP2D6 polymorphism and its impact on the clinical response to metoprolol: A systematic review and meta-analysis. Br J Clin Pharmacol, 2020. 86(6): p. 1015–1033.32090368
69 Parvez, B., N. Chopra, S. Rowan, J.C. Vaglio, et al., A common beta1-adrenergic receptor polymorphism predicts favorable response to rate-control therapy in atrial fibrillation. J Am Coll Cardiol, 2012. 59(1): p. 49–56.22192668
70 Lymperopoulos, A. and A. Bathgate, Pharmacogenomics of the heptahelical receptor regulators G-protein-coupled receptor kinases and arrestins: the known and the unknown. Pharmacogenomics, 2012. 13(3): p. 323–41.22304582
71 Huntgeburth, M., K. La Rosee, H. ten Freyhaus, M. Bohm, et al., The Arg389Gly beta1-adrenoceptor gene polymorphism influences the acute effects of beta-adrenoceptor blockade on contractility in the human heart. Clin Res Cardiol, 2011. 100(8): p. 641–7.21311897
72 Liu, J., Z.Q. Liu, Z.R. Tan, X.P. Chen, et al., Gly389Arg polymorphism of beta1-adrenergic receptor is associated with the cardiovascular response to metoprolol. Clin Pharmacol Ther, 2003. 74(4): p. 372–9.14534524
73 Chen, L., T. Xiao, L. Chen, S. Xie, et al., The Association of ADRB1 and CYP2D6 Polymorphisms With Antihypertensive Effects and Analysis of Their Contribution to Hypertension Risk. Am J Med Sci, 2018. 355(3): p. 235–239.29549925
74 Raimoglou, D., C. Izgi, R. Enar, M.H. Karpuz, et al., Structural and Functional Impact of Adrenoceptor Beta-1 Gene Polymorphism in Patients with Hypertrophic Cardiomyopathy and Response to Beta-Blocker Therapy. Anatol J Cardiol, 2024. 28(3): p. 150–157.38419512
75 Davis, B.H., K. Williams, D. Absher, B. Korf, et al., Evaluation of population-level pharmacogenetic actionability in Alabama. Clin Transl Sci, 2021. 14(6): p. 2327–2338.34121327
76 Guerra, L.A., C. Lteif, M.J. Arwood, C.W. McDonough, et al., Genetic polymorphisms in ADRB2 and ADRB1 are associated with differential survival in heart failure patients taking beta-blockers. Pharmacogenomics J, 2022. 22(1): p. 62–68.34642472
77 Terra, S.G., K.K. Hamilton, D.F. Pauly, C.R. Lee, et al., Beta1-adrenergic receptor polymorphisms and left ventricular remodeling changes in response to beta-blocker therapy. Pharmacogenet Genomics, 2005. 15(4): p. 227–34.15864115
78 Shahin, M.H., N.E. Rouby, D.J. Conrado, D. Gonzalez, et al., beta(2) -Adrenergic Receptor Gene Affects the Heart Rate Response of beta-Blockers: Evidence From 3 Clinical Studies. J Clin Pharmacol, 2019. 59(11): p. 1462–1470.31090079
79 Suonsyrja, T., K. Donner, T. Hannila-Handelberg, H. Fodstad, et al., Common genetic variation of beta1- and beta2-adrenergic receptor and response to four classes of antihypertensive treatment. Pharmacogenet Genomics, 2010. 20(5): p. 342–5.20300048
80 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.
81 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127–34.25974703
82 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, et al., Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89–99.35194175
83 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094–3118.34474980
84 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347–356.36739136
85 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116–3125.37277227
86 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564–9.26931183

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.