# Diazepam Therapy and CYP2C19 Genotype

## Introduction

Diazepam is a benzodiazepine with several clinical uses, including managing anxiety, insomnia, muscle spasms, seizures, and alcohol withdrawal (1). Brand names include Valium, Diastat Acudial, Diastat, and Diazepam Intensol.

Diazepam is primarily metabolized by CYP3A4 and CYP2C19 to the major active metabolite, desmethyldiazepam. Approximately 2% of Europeans, 13% of East Asians, and as much as 57% of Oceanians have reduced or absent CYP2C19 enzyme activity (“poor metabolizers”) (2).

The FDA-approved drug label for diazepam gel states that “the marked inter-individual variability in the clearance of diazepam reported in the literature is probably attributable to variability of CYP2C19”(3). However, the most recent drug label for oral formulations (tablet and liquid) only briefly discusses CYP2C19 in the context of potential drug interactions (Table 1)(1). Diazepam is available in multiple formulations including tablets (1), rectal gel (3), injectable solution (4), and oral solutions (5). The injectable solution does not discuss potential pharmacogenetic interactions with CYP2C19.

Table 1.

The FDA Diazepam Statements on Metabolism and Drug Interactions (2020, 2017)

Drug (formulation) | Metabolism and pharmacogenetic interactions
Diazepam (tablet, oral solution)^a^ | Diazepam is N-demethylated by CYP3A4 and 2C19 to the active metabolite N-desmethyldiazepam, and is hydroxylated by CYP3A4 to the active metabolite temazepam. […] There is a potentially relevant interaction between diazepam and compounds that inhibit certain hepatic enzymes (particularly CYP3A and CYP2C19). Data indicate that these compounds influence the pharmacokinetics of diazepam and may lead to increased and prolonged sedation. At present, this reaction is known to occur with cimetidine, ketoconazole, fluvoxamine, fluoxetine, and omeprazole.
Diazepam (gel)^b^ | The marked inter-individual variability in the clearance of diazepam reported in the literature is probably attributable to variability of CYP2C19 (which is known to exhibit genetic polymorphism; approximately 3–5% of Caucasians have little or no activity and are “poor metabolizers”) and CYP3A4. […] … Potential interactions may occur when diazepam is given concurrently with agents that affect CYP2C19 and CYP3A4 activity. Potential inhibitors of CYP2C19 and CYP3A4 could decrease the rate of diazepam elimination, while inducers of CYP2C19 and CYP3A4 could increase the rate of elimination of diazepam. Effect of diazepam on the metabolism of other drugs: There are no reports as to which isozymes could be inhibited or induced by diazepam. But, based on the fact that diazepam is a substrate for CYP2C19 and CYP3A4, it is possible that diazepam may interfere with the metabolism of drugs that are substrates for CYP2C19, (for example, omeprazole, propranolol, and imipramine) and CYP3A4 (for example, cyclosporine, paclitaxel, terfenadine, theophylline, and warfarin) leading to a potential drug-drug interaction.

^a^ Information adapted from (1, 5).

^b^ Information adapted from (3).

## Drug: Diazepam

Diazepam is used to manage anxiety disorders or for the short-term relief of the symptoms of anxiety. In acute alcohol withdrawal, diazepam may provide symptomatic relief from agitation, tremor, delirium tremens, and hallucinations. Diazepam is also useful as an adjunct treatment for the relief of acute skeletal muscle spasms, as well as spasticity caused by upper motor neuron disorders (1, 6).

There are 16 benzodiazepines licensed by the FDA. Diazepam was the second benzodiazepine to be used clinically (after chlordiazepoxide), after being approved for use in 1963. It remains a commonly used drug today, and is included in the World Health Organization’s core list of essential medicines needed for a basic healthcare system (7).

The use of benzodiazepines has replaced the use of barbiturates. Although these drug classes share similar therapeutic effects, barbiturates have a narrower therapeutic index, they are more sedative at therapeutic doses, and a barbiturate overdose is more likely to be fatal (8).

Like all benzodiazepines, diazepam is a controlled substance. Chronic use, either at standard therapeutic doses or through recreational abuse, can lead to tolerance and physical dependence. If diazepam treatment is abruptly discontinued, withdrawal symptoms can arise that can be severe and include seizures. Therefore, a gradual tapering of dose is recommended after chronic therapy.

Diazepam has several therapeutic effects—it is a sedative, anxiolytic, anticonvulsant muscle relaxant, and has amnesic effects. Diazepam is thought to exert these effects through an interaction with gamma-aminobutyric acid (GABA) A-type receptors (GABA_A_), and GABA is the major inhibitory neurotransmitter in the central nervous system. When GABA binds to the GABA_A_ receptor, the receptor opens, allowing the influx of chloride ions into neurons. This reduces the ability of neurons to depolarize and produce action potentials (excessive action potentials are implicated in seizures). It is thought that diazepam enhances the effects of GABA by increasing the affinity between GABA and its receptor, causing GABA to bind more tightly to the GABA_A_ receptor (1, 3).

Diazepam is primarily metabolized via CYP2C19 and CYP3A4 to the major active metabolite (desmethyldiazepam), which is found in the plasma at concentrations equivalent to diazepam. Two minor active metabolites include temazepam and oxazaepam, which are usually not detectable. Other cytochrome P450 (CYP) enzymes involved in diazepam metabolism include CYP2C9, CYP2B6, and CYP3A5 (9).

Safe and effective use of oral diazepam in pediatric individuals below the age of 6 months has not been established. Pharmacokinetics indicate that the mean half-life of diazepam in children aged 3–8 years old is less than 18 hours, with elimination half-lives in full-term infants closer to 30 hours. Diazepam rectal gel has been studied and shown to be effective in children 2 years or older; safety and efficacy has not been established in children under 2 (3). Diazepam can be transmitted in breast milk to nursing infants, thus breastfeeding is not recommended for individuals receiving oral diazepam (1). Diazepam and desmethyldiazepam have long half-lives, thus there is little to no benefit to timing of breastfeeding with respect to the dose of diazepam (10). Breastfeeding after acute use of diazepam gel is possible, though “an appropriate period of time” should pass between dosage and nursing (3).

The FDA-approved label for diazepam tablets states that there is a suggested increased risk of congenital malformations and other developmental abnormalities associated with benzodiazepine drug use during pregnancy. Neonatal flaccidity, respiratory and feeding difficulties, and hyopothermia have been reported in children born to mothers who have received benzodiazapines late in pregnancy or during labor and delivery. (1)

Both gel and tablet formulations of diazepam have reduced clearance and increased elimination half-lives in geriatric populations. This can alter the peak and trough concentrations for oral diazepam as well as the time to achieve steady state concentrations (1) and leads to a higher risk of ataxia or overdose in the gel formulation (3). Diazepam gel should be used with caution in individuals with compromised respiratory function (3). Similarly, individuals with renal or hepatic impairment should be administered oral or gel formulations of diazepam with caution, as these individuals have reduced clearance of diazepam and their metabolites (1, 3).

## Gene: CYP2C19

The CYP superfamily is a large and diverse group of hepatic enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs. The CYP genes are very polymorphic and can result in reduced, absent, or increased drug metabolism.

The CYP2C19 enzyme contributes to the metabolism of a range of clinically important drugs, including antidepressants, antiplatelet agents, antifungal agents, some proton pump inhibitors, and benzodiazepines such as diazepam.

The CYP2C19 gene is highly polymorphic, as there are over 35 variant star (*) alleles cataloged by the Pharmacogene Variation (PharmVar (https://www.pharmvar.org/)) Consortium. The CYP2C19*1 is considered the wild-type allele when no variants are detected and is associated with normal enzyme activity and the “normal metabolizer” phenotype.

The CYP2C19*17 allele is associated with increased enzyme activity and is found among individuals with ‘rapid’ (*1/*17) and ‘ultrarapid’ (*17/*17) metabolizer phenotypes. Heterozygous carriers of non-functional alleles (for example, *2 and *3) are classified as ‘intermediate metabolizers’ (for example, *1/*2), and individuals who have 2 non-functional alleles are classified as “poor metabolizers” (for example, *2/*2, *2/*3) (Table 2).

Table 2.

The CPIC Assignment of CYP2C19 Phenotype based on Genotype (2017)

Phenotype | Genotype | Examples of diplotypes
CYP2C19 ultrarapid metabolizer (approximately 2–5% of individuals)^a^ | An individual with 2 increased function alleles | *17/*17
CYP2C19 rapid metabolizer (approximately 2–30% of individuals) | An individual with one normal function allele and one increased function allele | *1/*17
CYP2C19 normal metabolizer (approximately 35–50% of individuals) | An individual with 2 normal function alleles | *1/*1
CYP2C19 intermediate metabolizer (approximately 18–45% of individuals) | An individual with one normal function allele and one no function allele or one no function allele and one increased function allele | *1/*2 *1/*3 *2/*17^b^
CYP2C19 poor metabolizer (approximately 2–15% of individuals) | An individual with 2 no function alleles | *2/*2 *2/*3 *3/*3

CPIC: Clinical Pharmacogenetics Implementation Consortium

^a^ CYP2C19 metabolizer status frequencies are based on average multi-ethnic frequencies. See the CYP2C19 Frequency Tables for population-specific allele and phenotype frequencies (11).

^b^ The predicted metabolizer phenotype for the*2/*17 genotype is a provisional classification. The available evidence indicates that the CYP2C19*17 increased function allele is unable to completely compensate for the CYP2C19*2 no function allele.

This CPIC table is adapted from (11).

## Linking Gene Variation with Treatment Response

It is well documented that wide inter-individual variation in the metabolism of benzodiazepines occurs, which includes diazepam metabolism. This can result in marked differences in drug levels when standard dosing is used and may potentially influence both therapeutic and adverse effects. It is thought that the variability in clearance of many benzodiazepines, including diazepam, is due to the variability in CYP2C19 and CYP3A4 genotypes (1, 9, 12, 13, 14).

## Genetic Testing

Clinical genotyping tests are available for several CYP2C19 alleles. The NIH’s Genetic Testing Registry (GTR) provides examples of the genetic tests that are available for the diazepam response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN077977) and the CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1557%255Bgeneid%255D). In addition, variant CYP2C19 alleles to be included in clinical genotyping assays have been recommended by the Association for Molecular Pathology (15).

Usually an individual’s result is reported as a diplotype, such as CYP2C19 *1/*1, and may also include an interpretation of the predicted metabolizer phenotype (ultrarapid, rapid, normal, intermediate, or poor). Table 2 summarizes common CYP2C19 phenotypes.

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2020 Statement from the US Food and Drug Administration (FDA): [Diazepam tablets, oral solution] Diazepam is N-demethylated by CYP3A4 and 2C19 to the active metabolite N-desmethyldiazepam, and is hydroxylated by CYP3A4 to the active metabolite temazepam.

[…]

There is a potentially relevant interaction between diazepam and compounds which inhibit certain hepatic enzymes (particularly CYP3A and CYP2C19). Data indicate that these compounds influence the pharmacokinetics of diazepam and may lead to increased and prolonged sedation. At present, this reaction is known to occur with cimetidine, ketoconazole, fluvoxamine, fluoxetine, and omeprazole.

Please review the complete therapeutic recommendations that are located here: ( 1 , 5 ).

2017 Statement from the US Food and Drug Administration (FDA): [Diazepam gel] The metabolism of diazepam is primarily hepatic and involves demethylation (involving primarily CYP2C19 and CYP3A4) and 3-hydroxylation (involving primarily CYP3A4), followed by glucuronidation. The marked inter-individual variability in the clearance of diazepam reported in the literature is probably attributable to variability of CYP2C19 (which is known to exhibit genetic polymorphism; about 3-5% of Caucasians have little or no activity and are “poor metabolizers”) and CYP3A4.

[…]

[underlined: Effect of Other Drugs on Diazepam Metabolism]: In vitro studies using human liver preparations suggest that CYP2C19 and CYP3A4 are the principal isozymes involved in the initial oxidative metabolism of diazepam. Therefore, potential interactions may occur when diazepam is given concurrently with agents that affect CYP2C19 and CYP3A4 activity. Potential inhibitors of CYP2C19 (for example, cimetidine, quinidine, and tranylcypromine) and CYP3A4 (for example, ketoconazole, troleandomycin, and clotrimazole) could decrease the rate of diazepam elimination, while inducers of CYP2C19 (for example, rifampin) and CYP3A4 (for example, carbamazepine, phenytoin, dexamethasone and phenobarbital) could increase the rate of elimination of diazepam.

[underlined: Effect of Diazepam on the Metabolism of Other Drugs]: There are no reports as to which isozymes could be inhibited or induced by diazepam. But, based on the fact that diazepam is a substrate for CYP2C19 and CYP3A4, it is possible that diazepam may interfere with the metabolism of drugs which are substrates for CYP2C19, (for example omeprazole, propranolol, and imipramine) and CYP3A4 (for example cyclosporine, paclitaxel, terfenadine, theophylline, and warfarin) leading to a potential drug-drug interaction.

Please review the complete therapeutic recommendations that are located here: ( 3 ).

## Nomenclature for selected CYP2C19 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2C19*2 | 681G>A Pro227Pro | NM_000769.1:c.681G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | NP_000760.1:p.Pro227= (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | rs4244285 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=4244285)
CYP2C19*3 | 636G>A Trp212Ter | NM_000769.1:c.636G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | NP_000760.1:p.Trp212Ter (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | rs4986893 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=4986893)
CYP2C19*17 | -806C>T | NM_000769.1:c.-806C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39357/) | Not applicable - variant occurs in a non-coding region | rs12248560 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=12248560)

dbSNP: The Single Nucleotide Polymorphism Database

Note: the normal “wild-type” allele is CYP2C19*1.

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (16).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Nomenclature for cytochrome P450 enzymes is available from Pharmacogene Variation (PharmVar (https://www.pharmvar.org/gene/cyp2c19)) Consortium.

Please note that the CYP2C19*2 defining variant (rs4244285) has recently been reported to be in high linkage disequilibrium with an intronic variant implicated in aberrant slicing (rs12769205) (17).

## Acknowledgments

The author would like to thank Megan Ehert, PharmD, MS, BCPP, Associate Professor of Pharmacy Practice and Science, University of Maryland School of Pharmacy, University of Maryland, Baltimore, MD, USA; and Bernard Esquivel MD, PhD, President of the Latin American Association for Personalized Medicine, Vancouver, BC, Canada for reviewing this summary.

2016 edition:

The author would like to thank Stuart Scott, Assistant Professor of Genetics and Genomic Sciences, Icahn School of Medicine at Mount Sinai, New York, NY, USA; Jitesh Kawedia, Pharmaceutical/Pharmacy Research Specialist at the University of Texas MD Anderson Cancer Center, Houston, TX, USA; Chakradhara Rao S. Uppugunduri, Maître-assistant at the CANSEARCH Laboratory, University of Geneva, Geneva, Switzerland; and Megan J. Ehret, PharmD, MS, BCPP Behavioral Health Clinical Pharmacy Specialist, Fort Belvoir Community Hospital, Fort Belvoir, VA, USA, for reviewing this summary.

## Version history

To view the 2016 version of this summary (created on 25 August 2016) please click here.

## References

1 DIAZEPAM tablet [package insert]. Greenville, NC, USA: Mayne Pharma Group Ltd; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=7d81850c-ad3f-4e2e-ac41-ed9c567aea4b.
2 CYP2C19 Frequency Table [Cited 15 September 2020]. Available from https://www.pharmgkb.org/page/cyp2c19RefMaterials.
3 DIAZEPAM- diazepam gel [package insert]. Bridgewater, NJ: Oceanside Pharmaceuticals; 2017. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=b1b2848b-b265-4f6f-9141-bf106dec0726.
4 DIAZEPAM- diazepam injection, solution [package insert]. Upper Saddle River, NJ: DASH Pharmaceuticals LLC; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=19d0e3e5-f081-4574-9f0a-e7e97a88c7a9.
5 DIAZEPAM- diazepam solution [package insert]. Eatontown, NJ: West-Ward Pharmaceuticals Corp.; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=9e85abed-1a8b-4762-a31f-f2c7f196b8af.
6 Kang, M., M.A. Galuska, and S. Ghassemzadeh, Benzodiazepine Toxicity, in StatPearls. 2020: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/29489152.
7 WHO Model Lists of Essential Medicines. Essential medicines and health products 2015 20 May 2016]; Available from: https://www.who.int/groups/expert-committee-on-selection-and-use-of-essential-medicines/essential-medicines-lists.
8 Mandrioli, R., L. Mercolini, and M.A. Raggi, Benzodiazepine metabolism: an analytical perspective. Curr Drug Metab, 2008. 9(8): p. 827-44.18855614
9 Fukasawa, T., A. Suzuki, and K. Otani, Effects of genetic polymorphism of cytochrome P450 enzymes on the pharmacokinetics of benzodiazepines. J Clin Pharm Ther, 2007. 32(4): p. 333-41.17635335
10 Diazepam, in Drugs and Lactation Database (LactMed). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000273.
11 Moriyama, B., A.O. Obeng, J. Barbarino, S.R. Penzak, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guidelines for CYP2C19 and Voriconazole Therapy. Clin Pharmacol Ther, 2017. 102(1): p. 45-51.27981572
12 Qin, X.P., H.G. Xie, W. Wang, N. He, et al., Effect of the gene dosage of CgammaP2C19 on diazepam metabolism in Chinese subjects. Clin Pharmacol Ther, 1999. 66(6): p. 642-6.10613621
13 Bertilsson, L., T.K. Henthorn, E. Sanz, G. Tybring, et al., Importance of genetic factors in the regulation of diazepam metabolism: relationship to S-mephenytoin, but not debrisoquin, hydroxylation phenotype. Clin Pharmacol Ther, 1989. 45(4): p. 348-55.2495208
14 Skryabin, V.Y., M.S. Zastrozhin, M.V. Torrado, E.A. Grishina, et al., How do CYP2C19*2 and CYP2C19*17 genetic polymorphisms affect the efficacy and safety of diazepam in patients with alcohol withdrawal syndrome? Drug Metab Pers Ther, 2020. 35(1).32134726
15 Pratt, V.M., A.L. Del Tredici, H. Hachad, Y. Ji, et al., Recommendations for Clinical CYP2C19 Genotyping Allele Selection: A Report of the Association for Molecular Pathology. J Mol Diagn, 2018. 20(3): p. 269-276.29474986
16 Kalman, L.V., J. Agundez, M.L. Appell, J.L. Black, et al., Pharmacogenetic allele nomenclature: International workgroup recommendations for test result reporting. Clin Pharmacol Ther, 2016. 99(2): p. 172-85.26479518
17 Chaudhry, A.S., B. Prasad, Y. Shirasaka, A. Fohner, et al., The CYP2C19 Intron 2 Branch Point SNP is the Ancestral Polymorphism Contributing to the Poor Metabolizer Phenotype in Livers with CYP2C19*35 and CYP2C19*2 Alleles. Drug Metab Dispos, 2015. 43(8): p. 1226-35.26021325

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance to nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Brivaracetam Therapy and CYP2C19 Genotype

Carisoprodol Therapy and CYP2C19 Genotype

Clobazam Therapy and CYP2C19 Genotype

Clopidogrel Therapy and CYP2C19 Genotype

Clozapine Therapy and CYP Genotype

Esomeprazole Therapy and CYP2C19 Genotype

Flibanserin Therapy and CYP2C19 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Lacosamide Therapy and CYP2C19 Genotype

Omeprazole Therapy and CYP2C19 Genotype

Prasugrel Therapy and CYP Genotype

Voriconazole Therapy and CYP2C19 Genotype

## Tests in GTR by Condition

Diazepam response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN077977&term=CN077977[DISCUI]&display_string=Diazepam response)

## Tests in GTR by Gene

CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1557[geneid]+AND+CN077977[cui])