# Clozapine Therapy and CYP Genotype

## Introduction

Clozapine is one of the most effective antipsychotics available in the treatment of schizophrenia and the only antipsychotic found to be effective in treatment-resistant schizophrenia (TRS). Clozapine is also used to reduce the risk of recurrent suicidal behavior in individuals with schizophrenia or schizoaffective disorder (1, 2).

Compared with typical antipsychotics, clozapine is far less likely to cause movement disorders, known as extrapyramidal side effects, which include dystonia, akathisia, parkinsonism, and tardive dyskinesia. However, there are significant risks associated with clozapine therapy that limits its use to only the most severely ill individuals who have not responded adequately to standard drug therapy. Most notably, because of the risk of clozapine-induced agranulocytosis, clozapine treatment requires monitoring of white blood cell counts (WBC) and absolute neutrophil counts (ANC), and in the US, the FDA requires that individuals receiving clozapine be enrolled in a computer-based registry (3). There is also a propensity for clozapine use to induce metabolic effects, resulting in substantial weight gain (1).

Clozapine is metabolized in the liver by the cytochrome P450 (CYP450) superfamily of enzymes. The CYP1A2 enzyme is the main CYP enzyme involved in clozapine metabolism, and CYP1A2 activity is a potential determinant of clozapine dose requirements (4). Other CYP enzymes involved in clozapine metabolism include CYP2D6, CYP3A4, and CYP2C19 (5).

The FDA-approved drug label states that a subset of the population (2–10%) have reduced activity of CYP2D6 (“poor metabolizers” [PMs]) and these individuals may develop higher than expected plasma concentrations of clozapine with typical standard doses. Therefore, the FDA states that a dose reduction may be necessary in individuals who are CYP2D6 PMs (Table 1) (1). However, the Dutch Pharmacogenetics Working Group (DPWG, Table 2) does not recommend dose alterations based on CYP2D6 genotype, though the gene-drug interaction is acknowledged (6). The DPWG further states that there is not a gene-drug interaction between CYP1A2 and clozapine due to the limited effect of known genetic variants on CYP1A2 function (6). Consequently, neither the FDA nor the DPWG recommend dose alterations based on CYP1A2 genotype.

Additionally, clozapine clearance is affected by gender, tobacco use, and ethnicity, with further contributions from pharmacologic interactions. Females have lower CYP1A2 enzyme activity than males. Non-smokers have lower CYP1A2 activity than smokers and Asians and Amerindians have lower activity than Caucasians. Clozapine clearance can also be affected by co-medications that induce or inhibit CYP1A2 and the presence of inflammation or obesity (7, 8).

Table 1.

The FDA Clozapine Dosage and CYP2D6 Poor Metabolizers (2020)

Phenotype | Dosing considerations
CYP2D6 poor metabolizers | Dose reduction may be necessary in individuals who are CYP2D6 poor metabolizers. Clozapine concentrations may be increased in these individuals, because clozapine is almost completely metabolized and then excreted.

This FDA table is adapted from (1).

Table 2.

The DPWG Recommendations for Clozapine and CYP2D6 (2016)

Phenotype | Dosing considerations
CYP2D6 poor metabolizer | No action is required for this gene-drug interaction.
CYP2D6 intermediate metabolizer | No action is required for this gene-drug interaction.
CYP2D6 ultrarapid metabolizer | No action is required for this gene-drug interaction.

This DPWG table is adapted from (6).

## Drug: Clozapine

Clozapine is an antipsychotic used in the treatment of schizophrenia. Schizophrenia is a severe psychiatric disorder with a worldwide prevalence of around 1%. The specific etiology of schizophrenia is unknown; however, it is largely considered to result from a combination of complex genetic, immunologic, and environmental factors.

The symptoms of schizophrenia fall into 3 main categories: positive, negative, and cognitive. Positive symptoms include reality distortion (for example, delusions, hallucinations) and thought disorders, which both can respond well to treatment. Negative symptoms are deficits in normal emotions and behavior and may be mistaken for depression. Symptoms divide into reduced expression of emotion (for example, speaking without moving or with a monotonous voice), and avolition (a lack of motivation to start or continue with a task). No treatment has established efficacy for these symptoms. Cognitive symptoms may also be difficult to recognize. They include poor executive functioning (understanding information and using it to make decisions) and trouble focusing or paying attention. Similarly, no treatment has major established efficacy.

The first antipsychotics to be discovered in the 1950s were haloperidol and chlorpromazine. Known as “first generation” or “typical” antipsychotics, these drugs are used to treat psychosis (regardless of the cause), chronic psychotic disorders (for example, schizophrenia), and other psychiatric conditions. However, prominent adverse effects included extrapyramidal side effects such as tardive dyskinesia, muscle rigidity, tremors, and Parkinsonian-like symptoms. Newer antipsychotics, known as “second generation” or “atypical” antipsychotics, have a lower risk of extrapyramidal side effects such as tardive dyskinesia. These medications include aripiprazole, clozapine, olanzapine, and risperidone. Apart from aripiprazole, atypical antipsychotics can have serious metabolic side effects.

Clozapine is unique among the antipsychotics as it effectively treats positive symptoms and appears to be more effective in treating negative symptoms, and some cognitive symptoms when compared with other antipsychotics that cause negative symptoms or impair cognition (9, 10, 11). Clozapine has also been shown to reduce aggression and reduce the risk of suicide, and is the only antipsychotic found to be effective in TRS (2, 12, 13, 14). More than one third of individuals are thought to have schizophrenia that only partially responds or is resistant to standard drugs; these individuals may then be treated with clozapine (2, 14, 15).

Clozapine was introduced in 1971; however, it was withdrawn in 1975 due to safety concerns, including severe neutropenia induced by the drug (11). This severely low level of neutrophils (a type of white blood cell) places individuals at high risk of potentially lethal infections. Given that clozapine was the most effective antipsychotic used to treat TRS, in 1989 the FDA reapproved clozapine for that use (9, 11, 13). The FDA defines TRS as severe schizophrenia that does not respond adequately to standard antipsychotic treatment (1).

The main action of both first- and second-generation antipsychotics appears to be the post-synaptic blockade of D2 dopamine receptors in the brain. An exception is aripiprazole, which is a D2 partial agonist. Blockade of the D2 receptor in the brain’s limbic system are thought to improve the “positive” symptoms of schizophrenia (16). However, because the first-generation antipsychotics also block dopamine receptors in the nigrostriatal pathway, they cause movement disorders known as extrapyramidal side effects. These disorders include akathisia (motor restlessness), dystonia (abnormal muscle tone), and tardive dyskinesia (involuntary and repetitive movements).

Clozapine only transiently occupies D2 receptors and then rapidly dissociates to allow normal dopamine neurotransmission. It is thought that because clozapine has a relatively low affinity for the D2 receptor and binds “loosely,” extrapyramidal side effects are less likely (15, 17). In addition to binding the D2 receptor, clozapine has a high affinity for the serotonin 5-HT_2A_ receptors. Blockade of 5-HT_2A_ in the mesocortical tract may also provide some protection against extrapyramidal side effects by increasing amounts of dopamine. Clozapine and its major metabolite (N-desmethylclozapine, also called norclozapine) have been shown to indirectly activate N-methyl-D-aspartate receptors and may also modulate gamma-aminobutyric acid and cholinergic pathways. However, despite these findings, it remains unclear what gives clozapine its superior efficacy to other antipsychotics (11).

Clozapine is primarily metabolized in the liver by the CYP450 superfamily of enzymes. The primary metabolic steps are demethylation to form norclozapine and oxidation to clozapine n-oxide. The major enzymes involved in clozapine demethylation are CYP3A4 and CYP1A2, with CYP2D6 playing a minor role. Oxidation is primarily catalyzed by CYP1A2 (18). Clozapine is almost completely metabolized before excretion. Norclozapine has limited activity in some brain receptors, while the clozapine n-oxide metabolite is inactive (1, 11, 19). Norclozapine is not an effective antipsychotic and may contribute to some of the clozapine adverse drug reactions (20, 21).

The most severe side effects of clozapine therapy are included in 5 boxed warnings on the drug label: 1) severe neutropenia, 2) seizures (more likely at higher doses), 3) myocarditis (inflammation of the heart muscle induced by clozapine that can be fatal), 4) increased mortality in elderly individuals with dementia-related psychosis, and 5) an increased risk of orthostatic hypotension, bradycardia, and syncope (1). Additional side effects include weight gain and metabolic changes, QT interval prolongation, gastrointestinal hypomobility with severe complications, eosinophilia, hepatotoxicity, neuroleptic malignant syndrome and pulmonary embolism (1).

Additionally, there is a high risk that individuals with TRS taking clozapine may develop pneumonia, with a population attributable risk of pneumonia in clozapine-medicated individuals with TRS of 64%. Individuals with TRS in the absence of clozapine therapy had an estimated population attributable risk of pneumonia of 45%, which has been attributed to smoking, medication issues, and obesity prevalence in the TRS population. Clozapine use may decrease immunoglobulin levels and increase the interleukin-1 receptor antagonist, putting individuals at a higher risk for community-acquired pneumonia. Many medications used for TRS, clozapine included, can also negatively affect swallowing, increase salivation and sedation, contributing to the risk of aspiration pneumonia (22, 23, 24)

Because of the risk of neutropenia, clozapine can only be prescribed according to a schedule that monitors the patient’s WBC and ANC. A severe neutropenia termed agranulocytosis is defined as an ANC of less than 500/mm^3^, is estimated to occur in around 1% of individuals, and could prove fatal if not detected early by regular monitoring (1, 25, 26). Before initiating clozapine therapy, baseline ANC must be obtained and monitored regularly during treatment. Clozapine therapy should be suspended if the ANC falls below 1500 and monitoring of ANC should be performed before reinitiating clozapine therapy (1).

Genetic risk factors for clozapine-induced neutropenia have been identified, consisting of 2 independent amino acid changes in HLA-DQB1 (126Q) and HLA-B (158T). The HLA-DQB1 gene is associated with autoimmune disease and HLA-B is an important component of severe drug reactions. Despite this genetic insight, a genetic test based solely on HLA-DQB1 and HLA-B would not be able to adequately identify if individuals are truly at low risk of clozapine-induced neutropenia (27). More recent studies have confirmed these risk-associated loci and suggested the SLCO1B3/SLCO1B7 locus as contributing to additional risk; however, these data do not support these loci having sufficient predictive power to recommend genetic testing (28).

A genetic variant in the ACKR1 gene, commonly referred to as the Duffy-null genotype, causes a benign form of neutropenia usually called benign ethnic neutropenia (BEN) that can be mistaken for clozapine-induced neutropenia. This allele is common in individuals with African ancestry, but has also been reported in Middle Eastern, south west Asian and Oceania genetic backgrounds (28). For individuals known to have BEN, the FDA label indicates that a lower ANC is acceptable as compared with individuals without the Duffy-null genotype (1).

Therapeutic drug monitoring (TDM) may be employed in conjunction with the FDA-required ANC testing during treatment (29). A consensus guideline recommends a therapeutic range of 350–600 ng/ml for trough steady-state concentrations (30). The concentration to dose ratio is a useful clinical measure of clozapine clearance rates when determining appropriate dosage for individuals with altered CYP metabolic profiles, either due to genetic variation or comedication (29, 31). Moreover, the consensus guidelines strongly recommend clozapine TDM due to the narrow therapeutic range for this medication (30, 31). The importance of TDM in clozapine use is underscored by the observation that it was the third most toxic US medication between 1998-2005, when it was associated with 3277 deaths or serious non-fatal outcomes, lower than only oxycodone and fentanyl (32).

The use of clozapine in pregnancy has not been well-studied in humans, thus the FDA advises that clozapine tablets should only be used during pregnancy if clearly indicated. The increase of estrogen in the second and third trimester is associated with a decrease in the metabolism of CYP1A2 drugs. Thus, it is possible that clozapine levels may increase at the end of the pregnancy, though studies have been very limited (31). The FDA also states that clozapine is present in human breast milk and this poses a potential for serious adverse reactions in the nursing infants. A decision should be made whether to discontinue nursing or discontinue taking the drug. Additionally, safety and effectiveness in pediatric individuals has not been established (1).

## The Cytochrome P450 Family

The CYP450 superfamily is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs. The genes that encode CYP450 proteins are very polymorphic and can result in reduced, absent, or increased enzyme activity.

Other factors can affect CYP enzyme activity in addition to genetic variation, including concomitant medications. Inhibitors of CYP enzymes include the antibiotic ciprofloxacin (CYP1A2 inhibitor) and the antidepressant fluvoxamine (potent CYP1A2 and CYP2C19 inhibitor, moderate or weak inhibitor for CYP3A4, CYP2C9, and CYP2D6) (33). Inducers of the CYP enzymes include the antiseizure drug carbamazepine (CYP3A and CYP1A2 inducer), rifampin, phenytoin, phenobarbital, and St. John’s wort (all CYP3A4 inducers) (1, 34, 35).

In addition, other agents can influence CYP enzymes—caffeine and oral contraceptives are weak or moderate CYP1A2 inhibitors (36). Tobacco smoke has polycyclic aromatic hydrocarbons that bind the aryl hydrocarbon receptor, thereby increasing the expression of CYP1A2 (37). Thus, it is a weak inducer of CYP1A2 (1). Omeprazole has similar weak inducer properties and by binding the aryl hydrocarbon receptor, omeprazole increases the expression of CYP1A2. Thus, omeprazole has clinically relevant inducer effects on non-smokers (38).

Physiologic conditions can also alter CYP enzyme expression and activity. Studies have proposed that obesity may be associated with decreased clearance of clozapine, as well as other CYP1A2 substrates (39, 40, 41). Inflammation releases cytokines that inhibit CYPs including CYP1A2 (42). One study of post-surgery inflammation suggests that inflammation decreases CYP1A2 activity by half (43).

The phenomenon by which non-genetic factors alter the enzymatic phenotype typically associated with a particular genotype is termed phenoconversion. As discussed above, medications, other ingested substances, and physiologic conditions can alter the enzymatic activity of CYP proteins. For example, an individual with a genotype-predicted intermediate metabolizer (IM) status may have a clinical presentation more akin to a PM due to comedication with a known CYP enzyme inhibitor, such as ciprofloxacin.

## Gene: CYP1A2

Altered function of CYP1A2 influences the clearance of the clozapine (4). Understanding the full pharmacogenomic effects of CYP1A2 variation is still at an early stage compared with that of CYP2D6 and other CYP enzymes (44). The CYP1A2 enzyme is the main CYP enzyme involved in clozapine metabolism (4, 45).

The CYP1A2 enzyme comprises around 13% of all CYP protein in the liver, whereas CYP2D6 comprises around 2%. Approximately 25 variant CYP1A2 alleles have been reported, some of which have been shown to alter the activity of CYP1A2 (Table 3). For example, the *1C allele is associated with decreased enzyme activity (by altering the binding site of an unknown transcription factor in the gene promoter), and the *1F allele is associated with increased enzyme activity (by increasing the induction of expression) (44, 46).

The frequency of CYP1A2*1F (g.5732C>A in intron 1, rs762551) varies across populations. Studies have reported the frequency of the CYP1A2*1F allele to range from 54.9% in Africans to ~60% in Chinese and 68.2% in Caucasians (47, 48). The frequency of individuals who are heterozygous or homozygous for the CYP1A2*1F allele ranges from 57–69% in Czech and Hungarian populations and up to 73% in Turkish populations (49). The global average allele frequency of rs762551 (agnostic to potential other variants in cis) is 69.2%, but this ranges from 57% in South Asian populations up to 92% in other areas of Asia (50).

Additional rare alleles associated with decreased CYP1A2 activity include CYP1A2*7 and CYP1A2*6, both of which have been reported primarily in individuals of European ancestry, with the CYP1A2*7 allele being notably absent in a study of Chinese Han PMs (51, 52, 53). Other CYP1A2 alleles with low activity (*8, *15, *16, and *11) have been found in low numbers in East Asians (54). A study of 250 Japanese individuals found allele frequencies of 0.4% for CYP1A2*8, 0.2% for CYP1A2*15, and 0.2% for CYP1A2*16 (55).

As previously discussed, additional factors beyond genetic variation can influence CYP1A2 activity, resulting in phenoconversion.

Table 3.

Activity Status of Selected CYP1A2 Alleles

Allele type | CYP1A2 alleles
Normal function | *1A
Decreased function | *1C, *1K, *3, *4, *7, *8, *11, *15, *16
No function | *6
Increased function (inducible) | *1F

For a comprehensive list of CYP1A2 alleles, please see PharmVar (https://www.pharmvar.org/gene/CYP1A2).

## Gene: CYP2D6

The CYP2D6 enzyme is responsible for the metabolism of many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### CYP2D6 Alleles

The CYP2D6 gene on chromosome 22q13.2 is highly polymorphic. Over 140 star (*) alleles have been described and catalogued at the Pharmacogene Variation (PharmVar (https://www.pharmvar.org/gene/CYP2D6)) Consortium, and each allele is associated with either normal, decreased, absent, or unknown enzyme function (Table 4) (56).

The combination of CYP2D6 alleles that a person has is used to determine their diplotype (for example, CYP2D6 *4/*4). Based on function, each allele can be assigned an activity score from 0 to 1, which in turn is often used to assign a phenotype (for example, CYP2D6 PMs). When duplicated alleles are detected, both copies are assigned an activity score for phenotyping. However, the activity score system is not standardized across clinical laboratories or CYP2D6 genotyping platforms. The CPIC revised their activity scoring guidelines in October 2019 to promote harmonization. The CYP2D6 phenotype is defined by the sum of the 2 allele activity scores, which is most commonly in the range of 0 to 3.0 (57).

- Ultrarapid metabolizer (UM) has an activity score greater than 2.25
- Normal metabolizer phenotype (NM) has an activity score of 1.25 to 2.25
- Intermediate metabolizer (IM) has an activity score of >0 to <1.25
- Poor metabolizer (PM) has an activity score of 0 (14)

Table 4.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *27, *33 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See PharmVar (https://www.pharmvar.org/gene/CYP2D6).

The CYP2D6*1 allele is considered the wild-type allele when no variants are detected, which is associated with normal enzyme activity and the “normal metabolizer” phenotype. In addition, the CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, *5, and *6) (58, 59, 60, 61) or an enzyme with decreased activity (for example, *10, *17, and *41) (62, 63, 64) (see Table 4). There are large inter-ethnic differences in the frequency of these alleles, with *3, *4, *5, *6, and *41 being more common in Caucasians, *17 more common in Africans, and *10 more common in Asians (65).

Allele Frequencies Vary between Populations

Among Asians and in individuals of Asian descent, only approximately 50% of CYPD6 alleles are normal function, and the frequency of CYP2D6 duplications is as high as 45%, although this may have been overestimated by not accounting for tandem hybrid alleles (for example, *36+*10) (66). Other studies of a US individual population suggested less than 50% of alleles detected within Asian-descent individuals are normal-function alleles in a single copy, with 30% of alleles arising from structural variants (duplications or deletions) (67). Common no-function variants are CYP2D6*36 and CYP2D6*4 (67). Both these alleles contain the variant “c.100C>T,” which is the defining variant in CYP2D6*10 (see Allele Nomenclature table) (65, 66, 68, 69). The CYP2D6*36 allele is the result of a gene conversion event with the pseudogene CYP2D7 (70). This no-function allele is most commonly found in individuals of Asian ancestry (67).

Among Africans and African Americans, approximately 50% of CYP2D6 alleles are normal function (58, 64, 65, 71). African Americans also have been found to have a higher frequency of no-function structural variants or decreased-function single-copy variant alleles versus Caucasian or Hispanic-Americans (67). Intermediate and NM alleles are present in approximately 80% of the population of individuals of African descent (72).

Middle Eastern countries show a great diversity in phenotypic and allelic distribution for CYP2D6 (73), though on average, these individuals show a lower frequency of PM phenotypes (0.91%) and higher UM phenotypes than other ethnicities (74). The highest frequencies of CYP2D6 UM reported to date are 20% in Oceanians and 9.5% Near Easterners (72, 75).

Among European countries, there is diversity of allelic distribution (76). Gene duplications were more common in the south-eastern countries (Greece, Turkey: 6%) and less common in north-western countries (Sweden and Denmark, <1%). Meanwhile, CYP2D6*4 and *5 alleles were generally more common in the north and less common in the south (76). Worldwide CYP2D6 genotype and phenotype frequencies have been catalogued and recently published (74).

## Gene: CYP3A4

In contrast to CYP2D6, CYP1A2, and other genes that encode drug-metabolizing enzymes, CYP3A4 shows little genetic variation with known functional consequences (Table 5). Although around 40 variant CYP3A4 alleles have been reported, most have not been shown to alter the activity of CYP3A4 (77, 78). To date, only 3 loss-of-function CYP3A4 alleles have been identified (CYP3A4*6, CYP3A4*20 and CYP3A4*26) (79, 80).

The CYP3A4*22 allele has decreased function and explains 12% of the variation in CYP3A4 activity (81). This variant that is present in 3.2–10.6% of the Dutch population and 5.2–8.3% of the population in America (82). The Allele Frequency Aggregator project reports this reduced-function allele to be present in approximately 5% of the global population, with the lowest prevalence in Asian and African populations (83). The 1000 Genomes Project phase 3 data release estimates global prevalence to be slightly lower (~1%); a minor allele frequency of 5% is reported for the European average (84).

The CYP3A4*20 allele contains a premature stop codon that results in a loss-of-function of CYP3A4. It appears to be the most common CYP3A4-defective allele but is still relatively rare, with approximately 0.2% of European Americans and 0.05% African Americans who are heterozygous. However, in Spain, the CYP3A4*20 allele is present in 1.2% of the population, and up to 3.8% in specific Spanish regions (79).

Table 5.

Activity Status of Selected CYP3A4 Alleles

Allele type | CYP3A4 alleles
Normal function | *1A
Decreased function | *16A, *16B, *22
No function | *6, *20, *26

For a comprehensive list of CYP3A4 alleles, please see PharmVar (https://www.pharmvar.org/gene/CYP3A4).

## Gene: CYP2C19

Another CYP enzyme with a minor contribution to clozapine metabolism is CYP2C19. The CYP2C19 enzyme contributes to the metabolism of a range of clinically important drugs, including antidepressants, antiplatelet agents, anti-fungal agents, some proton pump inhibitors, and benzodiazepines such as diazepam.

The CYP2C19 gene is highly polymorphic, as there are over 35 variant star (*) alleles catalogued by the Pharmacogene Variation (PharmVar (https://www.pharmvar.org/)) Consortium. The CYP2C19*1 is considered the wild-type allele when no variants are detected and is associated with normal enzyme activity and the “normal metabolizer” phenotype.

The CYP2C19*17 allele is associated with increased enzyme activity and is found among individuals with ‘rapid’ (*1/*17) and ‘ultrarapid’ (*17/*17) metabolizer phenotypes. Individuals who have one copy of non-functional alleles (for example, *2 and *3) are classified as ‘intermediate metabolizers’ (for example, *1/*2), and individuals who have 2 non-functional alleles are classified as “poor metabolizers” (for example, *2/*2, *2/*3) (Table 6).

Table 6.

The CPIC Assignment of CYP2C19 Phenotype based on Genotype (2017)

Phenotype | Genotype | Examples of diplotype
CYP2C19 ultrarapid metabolizer (approximately 2–5% of individuals)^a^ | An individual with 2 increased-function alleles | *17/*17
CYP2C19 rapid metabolizer (approximately 2–30% of individuals) | An individual with one normal-function allele and one increased-function allele | *1/*17
CYP2C19 normal metabolizer (approximately 35–50% of individuals) | An individual with 2 normal-function alleles | *1/*1
CYP2C19 intermediate metabolizer (approximately 18–45% of individuals) | An individual with one normal-function allele and one no-function allele or one no-function allele and one increased-function allele | *1/*2 *1/*3 *2/*17b
CYP2C19 poor metabolizer (approximately 2–15% of individuals) | An individual with 2 no-function alleles | *2/*2 *2/*3 *3/*3

CPIC: Clinical Pharmacogenetics Implementation Consortium

^a^ CYP2C19 metabolizer status frequencies are based on average multi-ethnic frequencies. See the CYP2C19 Frequency Tables for population-specific allele and phenotype frequencies (85).

^b^ The predicted metabolizer phenotype for the*2/*17 genotype is a provisional classification. The available evidence indicates that the CYP2C19*17 increased-function allele is unable to completely compensate for the CYP2C19*2 no-function allele.

This CPIC table is adapted from (85).

It has been reported that approximately 2% of Caucasians, 4% of African Americans, and 14% of Chinese are CYP2C19 PMs; and up to 45% of individuals are CYP2C19 IMs (86). Other studies have found PM phenotypes to range between 10.8–16.4% in Asian populations, 3% in African descendants, and 1.6% in Middle Eastern populations (87, 88). Pacific Islanders have been reported to have higher frequencies of PMs—11.8% (88). The frequency of IMs is similarly distributed, higher in East and South Asian and Pacific Islander, lower in African or Middle Eastern populations (87).

The FDA-approved drug label for omeprazole, a CYP2C19 substrate, states that approximately 15–20% of Asians are CYP2C19 PMs, compared with 3% of Caucasians (89). The most common no-function allele is CYP2C19*2, which contains a c.681G>A variant in exon 5 that results in an aberrant splice site. This leads to the production of a truncated and non-functioning protein. The CYP2C19*2 allele frequencies are ~15% in Caucasians of European descent and Africans, and ~27–36% in Asians (87, 90).

The CYP2C19*3 allele is another commonly identified no-function variant, which contains a c.636G>A variant in exon 4 that causes a premature stop codon. The CYP2C19*3 allele frequencies are ~2–7% in Asian populations (90), but rare in other racial groups. Other no-function variants occur in less than 1% of the general population and include CYP2C19*4-*8 (91, 92).

The CYP2C19*17 allele, which results in rapid and UMs, has frequencies of only 1.3–4% among Asian populations compared with approximately 20–33.7% of African, European, and Near-Eastern populations (87, 88).

## Linking Gene Variation with Treatment Response

There is growing evidence to support that genetic factors, such as CYP2D6, play a role in determining the clinical outcome of antipsychotic treatment. However, there is no definitive evidence for clozapine treatment with regard to CYP1A2, CYP2D6, CYP3A4 or CYP2C19, with the latter 3 playing a minor role in clozapine metabolism. Although pharmacogenetic testing is available, its use in personalizing antipsychotic treatment is minimal (93). While the FDA recommends adjusting dosage only for CYP2D6 PMs, studies investigating the potential benefit of pharmacogenomic-guided dosing have studied CYP1A2, CYP2C19, and CYP3A status (93, 94).

There is no consensus on the effect of various CYP1A2 alleles on clozapine treatment, however, mounting evidence exists to suggest that changes in CYP1A2 activity can significantly affect clozapine plasma levels. Increased CYP1A2 activity is predicted to result in a more rapid metabolism of clozapine and lower clozapine half-life; conversely, reduced CYP1A2 activity would lead to reduced clozapine metabolism and a longer clozapine half-life (1, 18, 29). Cessation of smoking or co-medication with CYP1A2 inhibitors (for example, ciprofloxacin, fluvoxamine, or enoxacin) have led to an increase in clozapine exposure (95). Differences in gender and smoking status influence clozapine plasma levels. At least one case has been documented where high caffeine consumption was associated with an UM phenotype (40). Given that smoking is more common among individuals with schizophrenia than in the general population, the effect of tobacco use on CYP1A2 metabolism is particularly important for clozapine therapy (96). Multiple reports have found that infections, particularly pneumonia, are associated with risk of clozapine intoxication due to the release of cytokines (97, 98, 99). The decrease of clozapine clearance during infections is not specific; any inflammation with systemic manifestations, such as fever or serum C-reactive protein (CRP) elevations, can cause elevated clozapine serum concentrations. Thus, CRP elevations can help identify inflammation as a cause of clozapine concentration elevations (100). In one study, only 11% of individuals with concurrent infections during clozapine therapy were able to continue their medication without dose alteration (101).

Studies suggest that the required dose to maintain therapeutic plasma concentrations in individuals with Asian Indian and Southeast Asian ancestry is half of the dose of an individual with European ancestry, though the exact mechanism remains to be elucidated (29, 102). Several reports have documented that clozapine is used at lower doses in Asian individuals and that east Asians have a lower clozapine clearance as compared with Caucasians (53, 103, 104, 105). Similarly, studies of CYP1A2 activity have found Caucasians to have higher average enzyme activity than Asians (106). Typical clozapine doses in Asians range from 150–300 mg/day (40). Native Americans and other Amerindians may have clozapine metabolism similar to Asians and need similar lower doses as compared with Caucasians (107). A recent case of myocarditis in a Canadian of South Asian ancestry indicates that this dosing difference may be clinically relevant since the individual developed a clozapine-induced myocarditis when started with a Canadian typical titration with an initial dose of 25 mg/day and 100 mg/day was reached in the 11 day. On the other hand, a slower titration (initial dose 6.5 mg/day and final dose 81.25 mg/day) was tolerated without myocarditis (108). Furthermore, an analysis of 6 combined studies of European Caucasians established that the minimal therapeutic doses ranged from 236 (female non-smokers) to 368 mg/d (male smokers). These dosages are much lower than the ones proposed by the US clozapine package insert, which recommends targeting doses from 300-450 mg/day and then consider increases by 100 mg/day, up to 900 mg/day in rare situations (109). Thus, determination of CYP1A2 metabolizer status should account for not only genotype, but gender, obesity, inflammation, smoking or comedication, and ethnic background as potential confounding factors leading to phenoconversion (8).

Case studies have reported individuals with one or more copies of the increased-function allele CYP1A2*1F who responded poorly to clozapine therapy. However, evidence for a universal, clinically significant effect of CYP1A2*1F alleles on CYP1A2 is lacking. Out of the 7 kinetic studies, ranging in size from 58–185 individuals, only one medium-sized study (95 individuals) found a significant effect of the *1F allele on clozapine pharmacokinetics (110, 111, 112, 113, 114, 115, 116).

The FDA drug label indicates that individuals taking strong CYP1A2 inhibitors should take a significantly reduced dose of clozapine, due to reduced clearance via CYP1A2 metabolism (1). However, experts strongly caution against co-prescribing CYP1A2 inhibitors such as fluvoxamine or ciprofloxacin with clozapine due to potentially fatal drug-drug interactions (117, 118).

While the FDA-approved drug label states that dose adjustments may be required for CYP2D6 PMs, there are no specific guidelines from any pharmacogenomic authority to pre-emptively adjust an individual’s clozapine dosage based on CYP2D6 genotype. Case studies have reported altered pharmacodynamics in CYP2D6 PMs and UMs, however, further analysis suggests that phenoconversion due to comedication has a larger effect on CYP2D6-mediated clozapine metabolism than genotype alone (119, 120, 121, 122). Indeed, in vitro analysis suggests the CYP2D6 enzyme is responsible for approximately 6% of clozapine metabolism, further supporting a modest role for this enzyme in clinical management (5). Similarly, CYP3A4 genotypes have not been definitively shown to be associated with a specific response or altered dosage of clozapine, likely due to the primary role of CYP1A2 in clozapine metabolism (94, 114). However, one study suggests that CYP3A4 activity may play a role in metabolic side effects from clozapine therapy (123).

Multiple studies have examined the effect of CYP2C19 genotypes on the response to antipsychotics, including clozapine, with variable conclusions being reached to determine genotype-based guidance for clozapine. Genotypes studied include CYP2C19*2 and CYP2C19*17 (53, 124, 125).

## Genetic Testing

Genetic testing is available for common CYP2D6 (https://www.ncbi.nlm.nih.gov/gtr/genes/1565/), CYP1A2 (https://www.ncbi.nlm.nih.gov/gtr/genes/1544/), CYP3A4 (https://www.ncbi.nlm.nih.gov/gtr/genes/1576/) and CYP2C19 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CYP2C19) alleles. Often a panel of tests is performed. These panels test for variants in multiple genes, which are involved in the metabolism of many drugs, including clozapine. For examples of the tests available for the clozapine drug response (https://www.ncbi.nlm.nih.gov/gtr/conditions/CN077971/), please see the NIH Genetic Testing Registry.

Results are typically reported as a diplotype, such as CYP2D6 *1/*1. A result for copy number, if available, is also important when interpreting CYP2D6 results (126). Gene duplications and multiplications can be denoted by “xN”, for example: CYP2D6*1xN with xN representing the number of CYP2D6 gene copies. Note: representation of duplications is also not standardized among laboratories.

In 2018, the Association for Molecular Pathology (AMP) published recommendations for CYP2C19 genotyping allele selection. The recommendations determined varying tiers of alleles, based on the strength of evidence supporting drug response, minor allele frequencies and availability of reference materials. The AMP’s tier one group represent the core alleles recommended for genotyping panels: *2, *3, and *17 (127). These guidelines provide information for laboratories performing CYP2C19 genotype testing and are a useful complement to CPIC prescribing recommendations.

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2020 Statement from the US Food and Drug Administration (FDA)

Dosage Adjustments with Concomitant use of CYP1A2, CYP2D6, CYP3A4 Inhibitors or CYP1A2, CYP3A4 Inducers

Clozapine is a substrate for many cytochrome P450 isozymes, in particular CYP1A2, CYP3A4, and CYP2D6. Use caution when administering clozapine tablets concomitantly with drugs that are inducers or inhibitors of these enzymes.

[…]

Dose adjustments may be necessary in patients with concomitant use of:

- strong CYP1A2 inhibitors (e.g., fluvoxamine, ciprofloxacin, or enoxacin);
- moderate or weak CYP1A2 inhibitors (e.g., oral contraceptives, or caffeine);
- CYP2D6 or CYP3A4 inhibitors (e.g., cimetidine, escitalopram, erythromycin, paroxetine, bupropion, fluoxetine, quinidine, duloxetine, terbinafine, or sertraline);
- CYP3A4 inducers (e.g., phenytoin, carbamazepine, St. John’s wort, and rifampin);
- or CYP1A2 inducers (e.g., tobacco smoking)

[…]

Concomitant use of Strong CYP1A2 Inhibitors: Reduce clozapine tablets dose to one-third when coadministered with strong CYP1A2 inhibitors (e.g., fluvoxamine, ciprofloxacin, enoxacin).

Concomitant use of Strong CYP3A4 Inducers is not recommended.

Discontinuation of CYP1A2 or CYP3A4 Inducers: Consider reducing clozapine tablets dose when CYP1A2 inducers (e.g., tobacco smoke) or CYP3A4 inducers (e.g., carbamazepine) are discontinued.

Anticholinergic drugs: Concomitant use may increase the risk for anticholinergic toxicity.

[…]

Dose reduction may be necessary in patients who are CYP2D6 poor metabolizers. Clozapine concentrations may be increased in these patients, because clozapine is almost completely metabolized and then excreted.

[…]

A subset (3%–10%) of the population has reduced activity of CYP2D6 (CYP2D6 poor metabolizers). These individuals may develop higher than expected plasma concentrations of clozapine when given usual doses.

Please review the complete therapeutic recommendations that are located here: (1).

### Summary of recommendations from the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP) (2016, 2020)

CYP2D6 Poor, Intermediate or Ultrarapid Metabolizer-Clozapine [December 2020]

NO action is required for this gene-drug interaction.

The genetic variation results in a slightly elevated plasma concentration of clozapine, but there are no clinical consequences.

CYP1A2 [2016]

This is NOT a drug-gene interaction.

Please review the complete therapeutic recommendations that are located here: ( 6 ).

## Nomenclature for selected alleles

CYP1A2 Nomenclature

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP1A2*1C | -3860G>A -2964G>A | Unknown | Not applicable—variant occurs in a non-coding region | rs2069514 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=2069514)
CYP1A2*1K | -739T>G -729C>T -163C>A | NM_000761.5:c.-10+103T>G NM_000761.5:c.-10+113C>T NM_000761.5:c.-9-154C>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/511079/) | Not applicable—variant occurs in a non-coding region | rs2069526 (https://www.ncbi.nlm.nih.gov/snp/rs2069526) rs12720461 (https://www.ncbi.nlm.nih.gov/snp/rs12720461) rs762551 (https://www.ncbi.nlm.nih.gov/snp/rs762551)
CYP1A2*1F | -164C >A | NM_000761.4:c.-9-154C>A | Not applicable—variant occurs in a non-coding region | rs762551 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=762551)
CYP1A2*3 | 2116G>A; 5347T>C | NM_000761.5:c.1042G>A | NP_000752.2:p.Asp348Asn | rs56276455 (https://www.ncbi.nlm.nih.gov/snp/rs56276455)
CYP1A2*4 | 2499A>T; I386F | NM_000761.5:c.1156A>T | NP_000752.2:p.Ile386Phe | rs72547516 (https://www.ncbi.nlm.nih.gov/snp/rs72547516)
CYP1A2*6 | 5090C>T; R431W | NM_000761.5:c.1291C>T | NP_000752.2:p.Arg431Trp | rs28399424 (https://www.ncbi.nlm.nih.gov/snp/rs28399424)
CYP1A2*7 | 3533G>A | NM_000761.5:c.1253+1G>A | Splicing defect | rs56107638 (https://www.ncbi.nlm.nih.gov/snp/rs56107638)
CYP1A2*8 | 5347T>C; 5166G>A; R456H | NM_000761.5:c.1367G>A | NP_000752.2:p.Arg456His | rs72547517 (https://www.ncbi.nlm.nih.gov/snp/rs72547517)
CYP1A2*11 | 558C>A; F186L | NM_000761.5:c.558C>A | NP_000752.2:p.Phe186Leu | rs72547513 (https://www.ncbi.nlm.nih.gov/snp/rs72547513)

CYP1A2*1A is the wild-type allele and is determined to be present with no variants are detected.

CYP2D6 Nomenclature

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A+1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (128)

^[2]^ AMP Tier 2 allele, (128)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (129).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (130).

CYP3A4 Nomenclature

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP3A4*6 | 17661_17662insA 277Frameshift | NM_017460.5:c.830_831insA | NP_059488.2:p.Asp277Glufs | rs4646438 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=4646438)
CYP3A4*16A | [underlined: 554C>G, T185S] | NM_017460.6:c.554C>G | NP_059488.2:p.Thr185Ser | rs12721627 (https://www.ncbi.nlm.nih.gov/snp/rs12721627)
CYP3A4*16B | [underlined: 554C>G, T185S] | NM_017460.6:c.554C>G | NP_059488.2:p.Thr185Ser | rs12721627 (https://www.ncbi.nlm.nih.gov/snp/rs12721627)
CYP3A4*16B | 20230G>A (gDNA) | NM_017460.6:c.1026+12G>A | Not applicable—variant occurs in a non-coding region | rs2242480 (https://www.ncbi.nlm.nih.gov/snp/rs2242480)
CYP3A4*20 | 1461_1462insA 488Frameshift | NM_017460.5:c.1461dup | NP_059488.2:p.Pro488Thrfs | rs67666821 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=67666821)
CYP3A4*22 | 15389C>T (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=35599367) | NM_017460.6:c.522-191C>T | Not applicable—variant occurs in a non-coding region | rs35599367 (https://www.ncbi.nlm.nih.gov/snp/rs35599367)
CYP3A4*26 | 17633C>T R268Stop | NM_017460.6:c.802C>T | NP_059488.2:p.Arg268Ter | rs138105638 (https://www.ncbi.nlm.nih.gov/snp/rs138105638)

CYP3A4*1A is the wild-type allele and is determined to be present with no variants are detected.

CYP2C19 Nomenclature

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2C19*2 | 681G>A Pro227Pro | NM_000769.4:c.681G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | NP_000760.1:p.Pro227= (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | rs4244285 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=4244285)
CYP2C19*3 | 636G>A Trp212Ter | NM_000769.4:c.636G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | NP_000760.1:p.Trp212Ter (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | rs4986893 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=4986893)
CYP2C19*4 | 1A>G Met1Val | NM_000769.4:c.1A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/16900/) | NP_000760.1:p.Met1Val (https://www.ncbi.nlm.nih.gov/clinvar/variation/16900/) | rs28399504 (https://www.ncbi.nlm.nih.gov/snp/rs28399504)
CYP2C19*5 | 90033C>T Arg433Trp | NM_000769.4:c.1297C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16898/) | NP_000760.1:p.Arg433Trp (https://www.ncbi.nlm.nih.gov/clinvar/variation/16898/) | rs56337013 (https://www.ncbi.nlm.nih.gov/snp/rs56337013)
CYP2C19*6 | 12748G>A Arg132Gln | NM_000769.4:c.395G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39350/) | NP_000760.1:p.Arg132Gln (https://www.ncbi.nlm.nih.gov/clinvar/variation/39350/) | rs72552267 (https://www.ncbi.nlm.nih.gov/snp/rs72552267)
CYP2C19*7 | 19294T>A | NM_000769.4:c.819+2T>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39348/) | (Splice donor variant) | rs72558186 (https://www.ncbi.nlm.nih.gov/snp/rs72558186)
CYP2C19*8 | 12711T>C Trp120Arg | NM_000769.4:c.358T>C | NP_000760.1:p.Trp120Arg | rs41291556 (https://www.ncbi.nlm.nih.gov/snp/rs41291556)
CYP2C19*9 | 12784G>A Arg144His | NM_000769.4:c.431G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39352/) | NP_000760.1:p.Arg144His (https://www.ncbi.nlm.nih.gov/clinvar/variation/39352/) | rs17884712 (https://www.ncbi.nlm.nih.gov/snp/rs17884712)
CYP2C19*17 | -806C>T | NM_000769.4:c.-806C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39357/) | Not applicable - variant occurs in a non-coding region | rs12248560 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=12248560)

Note: when no variants are detected the genotype is designated as CYP2C19*1 and is considered the normal “wild-type” allele.

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (131).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium.

## Acknowledgments

Version 2

The authors would like to thank Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; Jose de Leon, MD, Professor, Department of Psychiatry, University of Kentucky, Lexington, KY, USA; Daniel J. Müller, Head, Pharmacogenetics Research Clinic, Centre for Addiction and Mental Health, and Associate Professor, Department of Psychiatry, University of Toronto, Toronto, ON, Canada for reviewing this summary.

2016 edition (Version 1.0)

The author would like to thank Anil K. Malhotra, MD, Director, Division of Psychiatry Research, The Zucker Hillside Hospital and Vice Chair of Research, Department of Psychiatry, Hofstra Northwell School of Medicine, Hempstead, NY, USA; William T. Carpenter Jr., MD, Professor of Psychiatry and Pharmacology, Maryland Psychiatric Research Center, University of Maryland School of Medicine, Baltimore, MD, USA; and Daniel J. Müller, Head, Pharmacogenetics Research Clinic, Centre for Addiction and Mental Health, and Associate Professor, Department of Psychiatry, University of Toronto, Toronto, ON, Canada for reviewing this summary.

## Version History

To view the previous version (1.0) of this chapter, published June 8, 2016, please click here.

A minor revision to this chapter was made (version 2.1) on January 17, 2025 to address formatting issues and update the CYP2D6 Allele nomenclature to include AMP Tier 1 and Tier 2 allele designations as well as additional citations for PharmVar and HGVS Nomenclature. There are no changes to prescribing recommendations in this revision.

## References

1 CLOZAPINE tablet [Package insert]. Princeton, NJ: Sun Pharmaceutical Industries; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=53bdb79c-c4cf-4818-b1f0-225e67a14536.
2 Sriretnakumar, V., E. Huang, and D.J. Muller, Pharmacogenetics of clozapine treatment response and side-effects in schizophrenia: an update. Expert Opin Drug Metab Toxicol, 2015: p. 1-23.26364648
3 Freudenreich, O. and J. McEvoy. Guidelines for prescribing clozapine in schizophrenia. UpToDate 2015 Oct 09, 2015 [cited 2015 December 14th]; Available from: http://www.uptodate.com/contents/guidelines-for-prescribing-clozapine-in-schizophrenia.
4 Doude van Troostwijk, L.J., R.P. Koopmans, H.D. Vermeulen, and H.J. Guchelaar, CYP1A2 activity is an important determinant of clozapine dosage in schizophrenic patients. Eur J Pharm Sci, 2003. 20(4-5): p. 451-7.14659489
5 Olesen, O.V. and K. Linnet, Contributions of five human cytochrome P450 isoforms to the N-demethylation of clozapine in vitro at low and high concentrations. J Clin Pharmacol, 2001. 41(8): p. 823-32.11504269
6 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. CYP2D6 : clozapine [Cited 01 May 2020]. Available from http://kennisbank.knmp.nl
7 de Leon, J., C.J. Ruan, G. Schoretsanitis, and C. De Las Cuevas, A Rational Use of Clozapine Based on Adverse Drug Reactions, Pharmacokinetics, and Clinical Pharmacopsychology. Psychother Psychosom, 2020. 89(4): p. 200-214.32289791
8 Ruan, C.J. and J. de Leon, Is there a future for CYP1A2 pharmacogenetics in the optimal dosing of clozapine? Pharmacogenomics, 2020. 21(6): p. 369-373.32308139
9 Breier, A., R.W. Buchanan, B. Kirkpatrick, O.R. Davis, et al., Effects of clozapine on positive and negative symptoms in outpatients with schizophrenia. Am J Psychiatry, 1994. 151(1): p. 20-6.8267129
10 Buchanan, R.W., A. Breier, B. Kirkpatrick, P. Ball, and W.T. Carpenter, Jr., Positive and negative symptom response to clozapine in schizophrenic patients with and without the deficit syndrome. Am J Psychiatry, 1998. 155(6): p. 751-60.9619146
11 Wenthur, C.J. and C.W. Lindsley, Classics in chemical neuroscience: clozapine. ACS Chem Neurosci, 2013. 4(7): p. 1018-25.24047509
12 Spivak, B., E. Shabash, B. Sheitman, A. Weizman, and R. Mester, The effects of clozapine versus haloperidol on measures of impulsive aggression and suicidality in chronic schizophrenia patients: an open, nonrandomized, 6-month study. J Clin Psychiatry, 2003. 64(7): p. 755-60.12934974
13 Kane, J., G. Honigfeld, J. Singer, and H. Meltzer, Clozapine for the treatment-resistant schizophrenic. A double-blind comparison with chlorpromazine. Arch Gen Psychiatry, 1988. 45(9): p. 789-96.3046553
14 Carpenter, W.T. and R.W. Buchanan, Lessons to take home from CATIE. Psychiatr Serv, 2008. 59(5): p. 523-5.18451009
15 Fakra, E. and J.M. Azorin, Clozapine for the treatment of schizophrenia. Expert Opin Pharmacother, 2012. 13(13): p. 1923-35.22803789
16 Goodnick, P.J. and J.M. Jerry, Aripiprazole: profile on efficacy and safety. Expert Opin Pharmacother, 2002. 3(12): p. 1773-81.12472374
17 Seeman, P., Atypical antipsychotics: mechanism of action. Can J Psychiatry, 2002. 47(1): p. 27-38.11873706
18 Thorn, C.F., D.J. Muller, R.B. Altman, and T.E. Klein, PharmGKB summary: clozapine pathway, pharmacokinetics. Pharmacogenet Genomics, 2018. 28(9): p. 214-222.30134346
19 Rajji, T.K., B.H. Mulsant, S. Davies, S.M. Kalache, et al., Prediction of working memory performance in schizophrenia by plasma ratio of clozapine to N-desmethylclozapine. Am J Psychiatry, 2015. 172(6): p. 579-85.25859763
20 Schoretsanitis, G., J.M. Kane, C.J. Ruan, E. Spina, et al., A comprehensive review of the clinical utility of and a combined analysis of the clozapine/norclozapine ratio in therapeutic drug monitoring for adult patients. Expert Rev Clin Pharmacol, 2019. 12(7): p. 603-621.31075044
21 Tan, M.S.A., F. Honarparvar, J.R. Falconer, H.S. Parekh, et al., A systematic review and meta-analysis of the association between clozapine and norclozapine serum levels and peripheral adverse drug reactions. Psychopharmacology (Berl), 2021.33410989
22 Schoretsanitis, G., C.J. Ruan, C. Rohde, H. Verdoux, et al., An update on the complex relationship between clozapine and pneumonia. Expert Rev Clin Pharmacol, 2021: p. 1-5.33307871
23 Villasante-Tezanos, A.G., C. Rohde, J. Nielsen, and J. de Leon, Pneumonia risk: approximately one-third is due to clozapine and two-thirds is due to treatment-resistant schizophrenia. Acta Psychiatr Scand, 2020. 142(1): p. 66-67.32415875
24 De Leon, J., E.J. Sanz, and C. De Las Cuevas, Data From the World Health Organization's Pharmacovigilance Database Supports the Prominent Role of Pneumonia in Mortality Associated With Clozapine Adverse Drug Reactions. Schizophr Bull, 2020. 46(1): p. 1-3.31901099
25 Wicinski, M. and M.M. Weclewicz, Clozapine-induced agranulocytosis/granulocytopenia: mechanisms and monitoring. Curr Opin Hematol, 2018. 25(1): p. 22-28.28984748
26 Miller, D.D., Review and management of clozapine side effects. J Clin Psychiatry, 2000. 61 Suppl 8: p. 14-7; discussion 18-9.10811238
27 Goldstein, J.I., L.F. Jarskog, C. Hilliard, A. Alfirevic, et al., Clozapine-induced agranulocytosis is associated with rare HLA-DQB1 and HLA-B alleles. Nat Commun, 2014. 5: p. 4757.25187353
28 Legge, S.E. and J.T. Walters, Genetics of clozapine-associated neutropenia: recent advances, challenges and future perspective. Pharmacogenomics, 2019. 20(4): p. 279-290.30767710
29 de Leon, J., Personalizing dosing of risperidone, paliperidone and clozapine using therapeutic drug monitoring and pharmacogenetics. Neuropharmacology, 2020. 168: p. 107656.31150659
30 Hiemke, C., N. Bergemann, H.W. Clement, A. Conca, et al., Consensus Guidelines for Therapeutic Drug Monitoring in Neuropsychopharmacology: Update 2017. Pharmacopsychiatry, 2018. 51(1-02): p. e1.
31 de Leon, J., G. Schoretsanitis, J.M. Kane, and C.J. Ruan, Using therapeutic drug monitoring to personalize clozapine dosing in Asians. Asia Pac Psychiatry, 2020. 12(2): p. e12384.32119764
32 Moore, T.J., M.R. Cohen, and C.D. Furberg, Serious adverse drug events reported to the Food and Drug Administration, 1998-2005. Arch Intern Med, 2007. 167(16): p. 1752-9.17846394
33 Spina, E. and J. de Leon, Clinically relevant interactions between newer antidepressants and second-generation antipsychotics. Expert Opin Drug Metab Toxicol, 2014. 10(5): p. 721-46.24494611
34 de Leon, J., V. Santoro, C. D'Arrigo, and E. Spina, Interactions between antiepileptics and second-generation antipsychotics. Expert Opin Drug Metab Toxicol, 2012. 8(3): p. 311-34.22332980
35 Schoretsanitis, G., E. Spina, C. Hiemke, and J. de Leon, A systematic review and combined analysis of therapeutic drug monitoring studies for long-acting paliperidone. Expert Rev Clin Pharmacol, 2018. 11(12): p. 1237-1253.30449206
36 Schoretsanitis, G., J.M. Kane, and J. de Leon, Adding Oral Contraceptives to Clozapine May Require Halving the Clozapine Dose: A New Case and a Literature Review. J Clin Psychopharmacol, 2020. 40(3): p. 308-310.32332470
37 de Leon, J., The effects of antiepileptic inducers in neuropsychopharmacology, a neglected issue. Part II: Pharmacological issues and further understanding. Rev Psiquiatr Salud Ment, 2015. 8(3): p. 167-88.26111722
38 Mookhoek, E.J. and A.J. Loonen, Retrospective evaluation of the effect of omeprazole on clozapine metabolism. Pharm World Sci, 2004. 26(3): p. 180-2.15230368
39 Diaz, F.J., R.C. Josiassen, and J. de Leon, The Effect of Body Weight Changes on Total Plasma Clozapine Concentrations Determined by Applying a Statistical Model to the Data From a Double-Blind Trial. J Clin Psychopharmacol, 2018. 38(5): p. 442-446.30106876
40 Ruan, C.J., C.Y. Wang, Y.L. Tang, S.K. Lin, et al., Exploring the Prevalence of Clozapine Phenotypic Poor Metabolizers in 4 Asian Samples: They Ranged Between 2% and 13. J Clin Psychopharmacol, 2019. 39(6): p. 644-648.31688448
41 Zarezadeh, M., A. Saedisomeolia, M. Shekarabi, M. Khorshidi, et al., The effect of obesity, macronutrients, fasting and nutritional status on drug-metabolizing cytochrome P450s: a systematic review of current evidence on human studies. Eur J Nutr, 2020.33141242
42 Shah, R.R. and R.L. Smith, Inflammation-induced phenoconversion of polymorphic drug metabolizing enzymes: hypothesis with implications for personalized medicine. Drug Metab Dispos, 2015. 43(3): p. 400-10.25519488
43 Lenoir, C., Y. Daali, V. Rollason, F. Curtin, et al., Impact of Acute Inflammation on Cytochromes P450 Activity Assessed by the Geneva Cocktail. Clin Pharmacol Ther, 2020.33341941
44 Thorn, C.F., E. Aklillu, T.E. Klein, and R.B. Altman, PharmGKB summary: very important pharmacogene information for CYP1A2. Pharmacogenet Genomics, 2012. 22(1): p. 73-7.21989077
45 Basile, V.S., V. Ozdemir, M. Masellis, M.L. Walker, et al., A functional polymorphism of the cytochrome P450 1A2 (CYP1A2) gene: association with tardive dyskinesia in schizophrenia. Mol Psychiatry, 2000. 5(4): p. 410-7.10889552
46 Arranz, M.J., E. Dawson, S. Shaikh, P. Sham, et al., Cytochrome P4502D6 genotype does not determine response to clozapine. Br J Clin Pharmacol, 1995. 39(4): p. 417-20.7640149
47 Qi, G.Z., Z.Y. Zhang, X. Wang, S.J. Yin, et al., Functional allele and genotype frequencies of CYP1A2, CYP2B6 and iNOS among mainland Chinese Tibetan, Mongolian, Uygur and Han populations. J Clin Pharm Ther, 2016. 41(1): p. 84-91.26763760
48 Qi, G., C. Han, Y. Sun, and Y. Zhou, Genetic insight into cytochrome P450 in Chinese from the Chinese Millionome Database. Basic Clin Pharmacol Toxicol, 2020. 126(4): p. 341-352.31661191
49 Dlouha, L., V. Adamkova, L. Sedova, V. Olisarova, et al., Five genetic polymorphisms of cytochrome P450 enzymes in the Czech non-Roma and Czech Roma population samples. Drug Metab Pers Ther, 2020. 35(2).32681777
50 rs762551 RefSNP Report- dbSNP- NCBI. 2020 21 April 2020 29 July 2020]; Available from: https://www.ncbi.nlm.nih.gov/snp/rs762551#frequency_tab
51 Allorge, D., D. Chevalier, J.M. Lo-Guidice, C. Cauffiez, et al., Identification of a novel splice-site mutation in the CYP1A2 gene. Br J Clin Pharmacol, 2003. 56(3): p. 341-4.12919186
52 Zhou, Y., M. Ingelman-Sundberg, and V.M. Lauschke, Worldwide Distribution of Cytochrome P450 Alleles: A Meta-analysis of Population-scale Sequencing Projects. Clin Pharmacol Ther, 2017. 102(4): p. 688-700.28378927
53 Ruan, C.J., Y.N. Zang, C.Y. Wang, Y.H. Cheng, et al., Clozapine Metabolism in East Asians and Caucasians: A Pilot Exploration of the Prevalence of Poor Metabolizers and a Systematic Review. J Clin Psychopharmacol, 2019. 39(2): p. 135-144.30811372
54 Ito, M., Y. Katono, A. Oda, N. Hirasawa, and M. Hiratsuka, Functional characterization of 20 allelic variants of CYP1A2. Drug Metab Pharmacokinet, 2015. 30(3): p. 247-52.26022657
55 Soyama, A., Y. Saito, N. Hanioka, K. Maekawa, et al., Single nucleotide polymorphisms and haplotypes of CYP1A2 in a Japanese population. Drug Metab Pharmacokinet, 2005. 20(1): p. 24-33.15770072
56 Reny, J.L. and P. Fontana, Antiplatelet drugs and platelet reactivity: is it time to halt clinical research on tailored strategies? Expert Opin Pharmacother, 2015. 16(4): p. 449-52.25495963
57 CPIC. CPIC® Guideline for Codeine and CYP2D6. 2019 October 2019 [cited 2020 2020 June ]; Available from: https://cpicpgx.org/guidelines/guideline-for-codeine-and-cyp2d6/.
58 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256-63.8287064
59 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Codeine and Morphine Pathway, Pharmacokinetics [Cited 2012 July 24]. Available from http://www.pharmgkb.org/pathway/PA146123006.
60 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6-13.15492763
61 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*1 [Cited 2020 June 11]. Available from http://www.pharmgkb.org/haplotype/PA165816576.
62 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*4 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816579.
63 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*6 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816581.
64 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816582.
65 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229-43.11972444
66 Ramamoorthy, A., D.A. Flockhart, N. Hosono, M. Kubo, et al., Differential quantification of CYP2D6 gene copy number by four different quantitative real-time PCR assays. Pharmacogenet Genomics, 2010. 20(7): p. 451-4.20421845
67 Del Tredici, A.L., A. Malhotra, M. Dedek, F. Espin, et al., Frequency of CYP2D6 Alleles Including Structural Variants in the United States. Front Pharmacol, 2018. 9: p. 305.29674966
68 Wu, X., L. Yuan, J. Zuo, J. Lv, and T. Guo, The impact of CYP2D6 polymorphisms on the pharmacokinetics of codeine and its metabolites in Mongolian Chinese subjects. Eur J Clin Pharmacol, 2014. 70(1): p. 57-63.24077935
69 Hosono, N., M. Kato, K. Kiyotani, T. Mushiroda, et al., CYP2D6 genotyping for functional-gene dosage analysis by allele copy number detection. Clin Chem, 2009. 55(8): p. 1546-54.19541866
70 Gaedigk, A., L.D. Bradford, S.W. Alander, and J.S. Leeder, CYP2D6*36 gene arrangements within the cyp2d6 locus: association of CYP2D6*36 with poor metabolizer status. Drug Metab Dispos, 2006. 34(4): p. 563-9.16415111
71 Sistonen, J., A. Sajantila, O. Lao, J. Corander, et al., CYP2D6 worldwide genetic variation shows high frequency of altered activity variants and no continental structure. Pharmacogenet Genomics, 2007. 17(2): p. 93-101.17301689
72 CYP2D6 Frequency Table [Cited 8 March 2021]. Available from https://www.pharmgkb.org/page/cyp2d6RefMaterials.
73 Khalaj, Z., Z. Baratieh, P. Nikpour, H. Khanahmad, et al., Distribution of CYP2D6 polymorphism in the Middle Eastern region. J Res Med Sci, 2019. 24: p. 61.31523247
74 Gaedigk, A., K. Sangkuhl, M. Whirl-Carrillo, T. Klein, and J.S. Leeder, Prediction of CYP2D6 phenotype from genotype across world populations. Genet Med, 2017. 19(1): p. 69-76.27388693
75 Bousman, C.A., S.A. Bengesser, K.J. Aitchison, A.T. Amare, et al., Review and Consensus on Pharmacogenomic Testing in Psychiatry. Pharmacopsychiatry, 2021. 54(1): p. 5-17.33147643
76 Petrovic, J., V. Pesic, and V.M. Lauschke, Frequencies of clinically important CYP2C19 and CYP2D6 alleles are graded across Europe. Eur J Hum Genet, 2020. 28(1): p. 88-94.31358955
77 Westlind-Johnsson, A., R. Hermann, A. Huennemeyer, B. Hauns, et al., Identification and characterization of CYP3A4*20, a novel rare CYP3A4 allele without functional activity. Clin Pharmacol Ther, 2006. 79(4): p. 339-49.16580902
78 PharmVar [Cited 2 April 2021]. Available from https://www.pharmvar.org/.
79 Apellaniz-Ruiz, M., L. Inglada-Perez, M.E. Naranjo, L. Sanchez, et al., High frequency and founder effect of the CYP3A4*20 loss-of-function allele in the Spanish population classifies CYP3A4 as a polymorphic enzyme. Pharmacogenomics J, 2015. 15(3): p. 288-92.25348618
80 Werk, A.N., S. Lefeldt, H. Bruckmueller, G. Hemmrich-Stanisak, et al., Identification and characterization of a defective CYP3A4 genotype in a kidney transplant patient with severely diminished tacrolimus clearance. Clin Pharmacol Ther, 2014. 95(4): p. 416-22.24126681
81 Wang, D., Y. Guo, S.A. Wrighton, G.E. Cooke, and W. Sadee, Intronic polymorphism in CYP3A4 affects hepatic expression and response to statin drugs. Pharmacogenomics J, 2011. 11(4): p. 274-86.20386561
82 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. General background text Phamracogenetics - CYP3A4 [Cited December 2020]. Available from http://kennisbank.knmp.nl
83 ALFA: Allele Frequency Aggregator. [Cited 19 Jan 2021]. Available from www.ncbi.nlm.nih.gov/snp/docs/gsr/alfa/
84 Yates, A.D., P. Achuthan, W. Akanni, J. Allen, et al., Ensembl 2020. Nucleic Acids Res, 2020. 48(D1): p. D682-D688.31691826
85 Moriyama, B., A.O. Obeng, J. Barbarino, S.R. Penzak, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guidelines for CYP2C19 and Voriconazole Therapy. Clin Pharmacol Ther, 2017. 102(1): p. 45-51.27981572
86 Hicks, J.K., K. Sangkuhl, J.J. Swen, V.L. Ellingrod, et al., Clinical pharmacogenetics implementation consortium guideline (CPIC) for CYP2D6 and CYP2C19 genotypes and dosing of tricyclic antidepressants: 2016 update. Clin Pharmacol Ther, 2017. 102(1): p. 37-44.27997040
87 Biswas, M., Global distribution of CYP2C19 risk phenotypes affecting safety and effectiveness of medications. Pharmacogenomics J, 2020.33082528
88 Ionova, Y., J. Ashenhurst, J. Zhan, H. Nhan, et al., CYP2C19 Allele Frequencies in Over 2.2 Million Direct-to-Consumer Genetics Research Participants and the Potential Implication for Prescriptions in a Large Health System. Clin Transl Sci, 2020. 13(6): p. 1298-1306.32506666
89 OMEPRAZOLE - omeprazole capsule, delayed release pellets [package insert]. Boca Raton, FL: BreckenridgePharmaceutical; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=a6db366e-03bc-4b14-95cc-817a8be11d15.
90 CYP2C19 frequency table [Cited November 2020]. Available from https://cpicpgx.org/guidelines/cpic-guideline-for-proton-pump-inhibitors-and-cyp2c19/.
91 PharmVar CYP2C19. November 2020]; Available from: https://www.pharmvar.org/gene/CYP2C19.
92 Botton, M.R., X. Lu, G. Zhao, E. Repnikova, et al., Structural variation at the CYP2C locus: Characterization of deletion and duplication alleles. Hum Mutat, 2019. 40(11): p. e37-e51.31260137
93 Arranz, M.J., A. Gonzalez-Rodriguez, J. Perez-Blanco, R. Penades, et al., A pharmacogenetic intervention for the improvement of the safety profile of antipsychotic treatments. Transl Psychiatry, 2019. 9(1): p. 177.31346157
94 Toth, K., G. Csukly, D. Sirok, A. Belic, et al., Potential Role of Patients' CYP3A-Status in Clozapine Pharmacokinetics. Int J Neuropsychopharmacol, 2017. 20(7): p. 529-537.28340122
95 Skogh, E., F. Bengtsson, and C. Nordin, Could discontinuing smoking be hazardous for patients administered clozapine medication? A case report. Ther Drug Monit, 1999. 21(5): p. 580-2.10519459
96 de Leon, J. and F.J. Diaz, A meta-analysis of worldwide studies demonstrates an association between schizophrenia and tobacco smoking behaviors. Schizophr Res, 2005. 76(2-3): p. 135-57.15949648
97 Raaska, K., V. Raitasuo, M. Arstila, and P.J. Neuvonen, Bacterial pneumonia can increase serum concentration of clozapine. Eur J Clin Pharmacol, 2002. 58(5): p. 321-2.12185555
98 de Leon, J. and F.J. Diaz, Serious respiratory infections can increase clozapine levels and contribute to side effects: a case report. Prog Neuropsychopharmacol Biol Psychiatry, 2003. 27(6): p. 1059-63.14499324
99 Clark, S.R., N.S. Warren, G. Kim, D. Jankowiak, et al., Elevated clozapine levels associated with infection: A systematic review. Schizophr Res, 2018. 192: p. 50-56.28392207
100 de Leon, J., C.J. Ruan, H. Verdoux, and C. Wang, Clozapine is strongly associated with the risk of pneumonia and inflammation. Gen Psychiatr, 2020. 33(2): p. e100183.32420521
101 Ruan, C.J., Y.N. Zang, Y.H. Cheng, C.Y. Wang, and J. de Leon, Around 3% of 1,300 Levels Were Elevated during Infections in a Retrospective Review of 131 Beijing Hospital In-Patients with More than 24,000 Days of Clozapine Treatment. Psychother Psychosom, 2020. 89(4): p. 255-257.32114581
102 Suhas, S., V. Kumar, D. Damodharan, P. Sharma, et al., Do Indian patients with schizophrenia need half the recommended clozapine dose to achieve therapeutic serum level? An exploratory study. Schizophr Res, 2020.32518001
103 de Leon, J., A.P. Rajkumar, A.R. Kaithi, G. Schoretsanitis, et al., Do Asian Patients Require Only Half of the Clozapine Dose Prescribed for Caucasians? A Critical Overview. Indian J Psychol Med, 2020. 42(1): p. 4-10.31997860
104 Chang, W.H., S.K. Lin, H.Y. Lane, W.H. Hu, et al., Clozapine dosages and plasma drug concentrations. J Formos Med Assoc, 1997. 96(8): p. 599-605.9290269
105 Chong, S.A. and L. Chua, Clozapine, Chinese and blood. Br J Psychiatry, 1997. 171: p. 89-90.9328508
106 Ghotbi, R., M. Christensen, H.K. Roh, M. Ingelman-Sundberg, et al., Comparisons of CYP1A2 genetic polymorphisms, enzyme activity and the genotype-phenotype relationship in Swedes and Koreans. Eur J Clin Pharmacol, 2007. 63(6): p. 537-46.17370067
107 Gonzalez-Esquivel, D.F., H. Jung-Cook, T. Baptista, and J. de Leon, Amerindians may need clozapine dosing similar to that of Asians. Rev Psiquiatr Salud Ment, 2020.
108 Danilewitz, M., R. Rafizadeh, and C.A. Bousman, Successful Clozapine Rechallenge After Suspected Clozapine-Associated Myocarditis: A Case Report. J Clin Psychopharmacol, 2021. 41(2): p. 218-220.33528148
109 Schoretsanitis, G., R.L. Smith, E. Molden, A. Solismaa, et al., European Whites May Need Lower Minimum Therapeutic Clozapine Doses Than Those Customarily Proposed. J Clin Psychopharmacol, 2021. 41(2): p. 140-147.33587398
110 Huang, H.C., A.C. Lua, L.S. Wu, B.J. Wu, et al., Cigarette smoking has a differential effect on the plasma level of clozapine in Taiwanese schizophrenic patients associated with the CYP1A2 gene -163A/C single nucleotide polymorphism. Psychiatr Genet, 2016. 26(4): p. 172-7.27203225
111 Olsson, E., G. Edman, L. Bertilsson, D.S. Hukic, et al., Genetic and Clinical Factors Affecting Plasma Clozapine Concentration. Prim Care Companion CNS Disord, 2015. 17(1).26137357
112 Viikki, M., O. Kampman, N. Seppala, N. Mononen, et al., CYP1A2 polymorphism -1545C > T (rs2470890) is associated with increased side effects to clozapine. BMC Psychiatry, 2014. 14: p. 50.24555493
113 Lee, S.T., S. Ryu, S.R. Kim, M.J. Kim, et al., Association study of 27 annotated genes for clozapine pharmacogenetics: validation of preexisting studies and identification of a new candidate gene, ABCB1, for treatment response. J Clin Psychopharmacol, 2012. 32(4): p. 441-8.22722500
114 Jaquenoud Sirot, E., B. Knezevic, G.P. Morena, S. Harenberg, et al., ABCB1 and cytochrome P450 polymorphisms: clinical pharmacogenetics of clozapine. J Clin Psychopharmacol, 2009. 29(4): p. 319-26.19593168
115 Kootstra-Ros, J.E., W. Smallegoor, and J. van der Weide, The cytochrome P450 CYP1A2 genetic polymorphisms *1F and *1D do not affect clozapine clearance in a group of schizophrenic patients. Ann Clin Biochem, 2005. 42(Pt 3): p. 216-9.15949157
116 van der Weide, J., L.S. Steijns, and M.J. van Weelden, The effect of smoking and cytochrome P450 CYP1A2 genetic polymorphism on clozapine clearance and dose requirement. Pharmacogenetics, 2003. 13(3): p. 169-72.12618594
117 Spina, E., M.A. Barbieri, G. Cicala, and J. de Leon, Clinically Relevant Interactions between Atypical Antipsychotics and Anti-Infective Agents. Pharmaceuticals (Basel), 2020. 13(12).33276675
118 Spina, E., C. Hiemke, and J. de Leon, Assessing drug-drug interactions through therapeutic drug monitoring when administering oral second-generation antipsychotics. Expert Opin Drug Metab Toxicol, 2016. 12(4): p. 407-22.26878495
119 Caetano, D. and I. Piatkov, Higher than expected clozapine serum level and clozapine/norclozapine ratio due to CYP450 gene polymorphisms. Per Med, 2015. 12(6): p. 555-558.29750612
120 Caetano, D. and I. Piatkov, Ultrarapid clozapine metabolism and CYP2D6 gene duplication in a patient with schizophrenia. Per Med, 2016. 13(2): p. 113-117.29749897
121 Reznik, R., R.Y.Y. Chen, and P. Stanford, Clozapine toxicity in a CYP2D6 poor metaboliser: Additive effects of haloperidol and valproate on clozapine metabolism. Australas Psychiatry, 2018. 26(6): p. 608-611.29737183
122 Lesche, D., S. Mostafa, I. Everall, C. Pantelis, and C.A. Bousman, Impact of CYP1A2, CYP2C19, and CYP2D6 genotype- and phenoconversion-predicted enzyme activity on clozapine exposure and symptom severity. Pharmacogenomics J, 2020. 20(2): p. 192-201.31616047
123 Menus, A., A. Kiss, K. Toth, D. Sirok, et al., Association of clozapine-related metabolic disturbances with CYP3A4 expression in patients with schizophrenia. Sci Rep, 2020. 10(1): p. 21283.33277605
124 Milosavljevic, F., N. Bukvic, Z. Pavlovic, C. Miljevic, et al., Association of CYP2C19 and CYP2D6 Poor and Intermediate Metabolizer Status With Antidepressant and Antipsychotic Exposure: A Systematic Review and Meta-analysis. JAMA Psychiatry, 2020.33237321
125 Rodrigues-Silva, C., A.T. Semedo, H. Neri, R.P. Vianello, et al., The CYP2C19*2 and CYP2C19*17 Polymorphisms Influence Responses to Clozapine for the Treatment of Schizophrenia. Neuropsychiatr Dis Treat, 2020. 16: p. 427-432.32103962
126 Crews, K.R., A. Gaedigk, H.M. Dunnenberger, T.E. Klein, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guidelines for Codeine Therapy in the Context of Cytochrome P450 2D6 (CYP2D6) Genotype. Clinical pharmacology and therapeutics, 2012. 91(2): p. 321-6.22205192
127 Pratt, V.M., A.L. Del Tredici, H. Hachad, Y. Ji, et al., Recommendations for Clinical CYP2C19 Genotyping Allele Selection: A Report of the Association for Molecular Pathology. J Mol Diagn, 2018. 20(3): p. 269-276.29474986
128 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.34118403
129 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564-9.26931183
130 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, and T.E. Klein, Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542-545.34091888
131 Kalman, L.V., J. Agundez, M.L. Appell, J.L. Black, et al., Pharmacogenetic allele nomenclature: International workgroup recommendations for test result reporting. Clin Pharmacol Ther, 2016. 99(2): p. 172-85.26479518

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance with nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Aripiprazole Therapy and CYP2D6 Genotype

Atomoxetine Therapy and CYP2D6 Genotype

Brivaracetam Therapy and CYP2C19 Genotype

CYP2D6 Overview: Allele and Phenotype Frequencies

Carisoprodol Therapy and CYP2C19 Genotype

Carvedilol Therapy and CYP2D6 Genotype

Clobazam Therapy and CYP2C19 Genotype

Clopidogrel Therapy and CYP2C19 Genotype

Codeine Therapy and CYP2D6 Genotype

Deutetrabenazine Therapy and CYP2D6 Genotype

Diazepam Therapy and CYP2C19 Genotype

Eliglustat Therapy and CYP2D6 Genotype

Esomeprazole Therapy and CYP2C19 Genotype

Flibanserin Therapy and CYP2C19 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Lacosamide Therapy and CYP2C19 Genotype

Metoprolol Therapy and CYP2D6 Genotype

Omeprazole Therapy and CYP2C19 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Prasugrel Therapy and CYP Genotype

Primaquine Therapy and G6PD and CYP2D6 Genotype

Propafenone Therapy and CYP2D6 Genotype

Risperidone Therapy and CYP2D6 Genotype

Tamoxifen Therapy and CYP2D6 Genotype

Thioridazine Therapy and CYP2D6 Genotypes

Tramadol Therapy and CYP2D6 Genotype

Valbenazine Therapy and CYP2D6 Genotype

Venlafaxine Therapy and CYP2D6 Genotype

Voriconazole Therapy and CYP2C19 Genotype

## Tests in GTR by Condition

Clozapine response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN077971&term=CN077971[DISCUI]&display_string=Clozapine response)

## Tests in GTR by Gene

CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1565[geneid]+AND+CN077971[cui])

CYP1A2 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1544[geneid]+AND+CN077971[cui])

CYP3A4 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1576[geneid]+AND+CN077971[cui])

CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1557[geneid]+AND+CN077971[cui])