# Capecitabine Therapy and DPYD Genotype

## Introduction

Capecitabine (brand name Xeloda) is a chemotherapy agent that belongs to the drug class of fluoropyrimidines. It is widely used in the treatment of several malignancies including colon cancer, metastatic colorectal cancer, and metastatic breast cancer. Capecitabine is a prodrug that is enzymatically converted to its active form, fluorouracil (also called 5-fluorouracil), which acts as an antimetabolite to slow tumor growth.

The DPYD gene encodes dihydropyrimidine dehydrogenase (DPD), an enzyme that catalyzes the rate-limiting step in fluorouracil metabolism. Dihydropyrimidine dehydrogenase inactivates 80–90% of 5-fluorouracil (5-FU) into 5,6-dihydro-fluorouracil. Genetic variants in the DPYD gene can lead to enzymes with reduced or absent activity. Individuals who have at least one copy of a nonfunctional DPYD variant (for example, c.1905+1G>A (formerly *2A; rs3918290) or c.1679T>G (p.I560S; formerly *13; rs55886062)) will not be able to metabolize fluorouracil at normal rates. Consequently, these individuals are at risk of potentially life-threatening fluorouracil toxicity, such as bone marrow suppression, gastrointestinal toxicity and, rarely, neurotoxicity. The prevalence of DPD partial deficiency varies in different populations but is approximately 3–5%. There is an FDA-approved antidote for 5-FU overdose: uridine triacetate. Overdose can occur in individuals with partial DPD deficiency taking either capecitabine or 5-FU.

The FDA-approved drug label for capecitabine states that no capecitabine dose has been proven safe in individuals with absent DPD activity, and that there is insufficient data to recommend a specific dose in individuals with partial DPD activity as measured by any specific test (Table 1) (1).

The Clinical Pharmacogenetics Implementation Consortium (CPIC) and the Dutch Pharmacogenetics Working Group (DPWG) have published dosing recommendations for fluoropyrimidines (capecitabine and fluorouracil) based on DPYD genotype (Tables 2 and 3). Both recommendations include dose reductions for intermediate metabolizers (with reduced enzyme activity), and avoiding fluorouracil and choosing an alternative agent for poor metabolizers (with absent enzyme activity) (2, 3, 4).

Table 1.

The FDA Drug Label for Capecitabine: Warning DPD Deficiency (2020)

Phenotype | Capecitabine
DPD deficiency | Increased risk of severe or fatal adverse reactions in individuals with low or absent dihydropyrimidine dehydrogenase (DPD) activity. Withhold or permanently discontinue capecitabine tablets in individuals with evidence of acute early-onset or unusually severe toxicity, which may indicate near complete or total absence of (DPD) activity. No capecitabine dose has been proven safe in individuals with absent DPD activity.

Please see Therapeutic Recommendations based on Genotype for more information from FDA. This table is adapted from (1).

Table 2.

The CPIC Recommended Dosing of Fluoropyrimidines (Capecitabine or 5-Fluorouracil) by DPD Phenotype (2017, Nov 2018 Update)

Phenotype | Implications for phenotypic measures | Activity score | Dosing recommendations | Classification of recommendations^a^
DPYD normal metabolizer | Normal DPD activity and “normal” risk for fluoropyrimidine toxicity. | 2 | Based on genotype, there is no indication to change dose or therapy. Use label-recommended dosage and administration. | Strong
DPYD intermediate metabolizer | Decreased DPD activity (leukocyte DPD activity at 30–70% that of the normal population) and increased risk for severe or even fatal drug toxicity when treated with fluoropyrimidine drugs. | 1-1.5 | Reduce starting dose by 50%, followed by dose titration based on clinical judgement (and ideally therapeutic drug monitoring) Individuals with homozygous c.[2846A>T];[2846A>T] genotype, a >50% reduction in starting dose may be warranted. | Moderate
DPYD poor metabolizer | Complete DPD deficiency and increased risk for severe or even fatal drug toxicity when treated with fluoropyrimidine drugs | 0.5 | Avoid use of 5-fluorouracil or 5-fluorouracil prodrug-based regimens. In the event, based on clinical advice, alternative agents are not considered a suitable therapeutic option, 5-fluorouracil should be administered at a strongly reduced dose^c^ with early therapeutic drug monitoring.^d^ | Strong
DPYD poor metabolizer | Complete DPD deficiency and increased risk for severe or even fatal drug toxicity when treated with fluoropyrimidine drugs | 0 | Avoid use of 5-fluorouracil or 5-fluorouracil prodrug-based regimens. | Strong

CPIC, Clinical Pharmacogenetics Implementation Consortium

DPD, dihydropyrimidine dehydrogenase.

^a^ Rating scheme is described in Supplement (2).

^b^ Increase the dose in individuals experiencing no or clinically tolerable toxicity in the first 2 cycles to maintain efficacy; decrease the dose in individuals who do not tolerate the starting dose to minimize toxicities.

^c^ If available, a phenotyping test (see main text for further details) should be considered to estimate the starting dose. In the absence of phenotyping data, a dose of <25% of the normal starting dose is estimated assuming additive effects of alleles on 5-FU clearance.

^d^ Therapeutic drug monitoring should be done at the earliest timepoint possible (for example, minimum timepoint in steady state) in order to immediately discontinue therapy if the drug level is too high.

This table is adapted from (2). Updated information for Intermediate Metabolizers from Nov 2018 update (5).

Note: The nomenclature used in this table reflects the standardized nomenclature for pharmacogenetic terms proposed by CPIC in a 2016 paper, “Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC)” (6).

Table 3.

The DPWG Recommendations for Capecitabine/Fluorouracil by DPD Gene Activity, Systemic Route of Administration (2019)

DPD gene activity score | Recommendation | Pharmacist text
Activity score 1.5 | Start with 50% of the standard dose or avoid fluorouracil and capecitabine. After starting treatment, the dose should be adjusted based on toxicity and effectiveness. Tegafur is not an alternative, as this is also metabolized by DPD. | The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose
Activity score 1.0 | Start with 50% of the standard dose or choose an alternative. Adjustment of the initial dose should be guided by toxicity and effectiveness. Tegafur is not an alternative, as this is also metabolized by DPD. | Genetic variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.
PHENO^1^ | It is not possible to recommend a dose adjustment for these individuals based on the genotype only. Determine the residual DPD activity in mononuclear cells from peripheral blood and adjust the initial dose based on phenotype and genotype or avoid fluorouracil and capecitabine. Tegafur is not an alternative, as this is also metabolized by DPD. | The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.
Activity score 0 | Avoid fluorouracil and capecitabine Tegafur is not an alternative, as this is also metabolized by DPD. If an alternative is not possible: determine the residual DPD activity in mononuclear cells from peripheral blood and adjust the initial dose accordingly. An individual with 0.5% of the normal DPD activity tolerated 0.8% of the standard dose (150 mg capecitabine every 5 days). An individual with undetectable DPD activity tolerated 0.43% of the standard dose (150 mg capecitabine every 5 days with every third dose skipped). | Genetic variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the standard dose is a more than 100-fold overdose.

1 Individual’s genotype does not accurately predict activity level, phenotyping required.

Please see Therapeutic Recommendations based on Genotype for more information from DPWG. This table is adapted from (3, 4). DPWG, Dutch Pharmacogenetics Working Group

## Drug Class: Fluoropyrimidines

Fluoropyrimidines are a class of antimetabolite drugs that are widely used in the treatment of cancer. Currently, there are 3 types of fluoropyrimidines in clinical use: capecitabine (oral – pill) and 5-fluorouracil (5-FU – IV), which are licensed for use in the US, and tegafur, which is not available in the US. Capecitabine and tegafur are both active precursors of fluorouracil.

Fluoropyrimidines are thought to exert their chemotherapeutic effects through several active metabolites. The main mechanism of action is thought to be the inhibition of thymidylate synthase, which plays an important part in the folate-homocysteine cycle, and purine and pyrimidine synthesis pathways. Active metabolites can also be incorporated into RNA and DNA, ultimately leading to cell death (7). Based on their mechanism of action, fluoropyrimidines are teratogenic, as they can cause fetal harm when administered to a pregnant woman (8).

Approximately 10–40% of individuals develop severe and potentially life-threatening toxicity early during treatment with fluoropyrimidines (9). This toxicity typically leads to an interruption or discontinuation of potentially effective anticancer therapy and may require an emergency room visit or hospitalization in severe instances (10).

The inter-individual variation in the occurrence and severity of adverse events in individuals receiving fluoropyrimidines can be partly explained by clinical factors, such as age and gender. However, much of the variability in adverse events remains unexplained (11).

Of the genetic factors thought to contribute to fluoropyrimidine intolerance, the DPYD gene has been the most studied. This gene encodes the primary enzyme involved in breaking down fluoropyrimidines to inactive metabolites. Individuals who have DPD deficiency have a significantly increased risk of severe fluoropyrimidine toxicity, and the stratification of individuals based on DPYD genotype may help prevent adverse events (12, 13, 14, 15, 16, 17).

## Drug: Capecitabine

Capecitabine is a chemotherapy used as an adjunct treatment for colon cancer, and as either monotherapy or part of combination therapy for metastatic colorectal cancer, metastatic breast cancer, pancreatic cancer, esophageal cancer, head and neck cancers and neuroendocrine tumors (NETs) (1, 18, 19, 20, 21).

Capecitabine is an orally administered prodrug, which is converted to its active form, fluorouracil, by thymidine phosphorylase, an enzyme that can be found in higher concentrations in tumors compared to normal tissue and plasma. Fluorouracil (5-flourouracil, 5-FU) is structurally similar to pyrimidines, and the enzyme that catalyzes the rate-limiting step in the breakdown of pyrimidines (DPD) also catalyzes the rate-limiting step in 5-FU catabolism. Dihydropyrimidine dehydrogenase catalyzes the conversion of fluorouracil to the non-cytotoxic dihydrofluorouracil (22).

Once capecitabine is activated to 5-FU, further metabolism generates 5-fluoro-2’-deoxyuridine monophosphate (FdUMP) and 5-fluorouridine triphosphate (FUTP). These 2 metabolites achieve cell injury by different mechanisms. The FdUMP targets thymidylate synthase (TS), inhibiting synthesis of an important DNA precursor. The FUTP is incorporated into RNA, leading to inhibition of RNA processing and protein synthesis. (1)

Uridine triacetate (brand name Vistogard) was approved December 11, 2015 as an antidote for fluorouracil and capecitabine overdose (23). Exogenous uridine competes with 5-FU for incorporation into RNA, thus diluting the toxic effects of high 5-FU levels. Uridine triacetate is 4–6-fold higher in bioavailability than equimolar doses of uridine (24).

Uridine triacetate is meant for overdose treatment of adults or children, however, it can be considered in situations of individuals with pharmacogenetic deficiency, which is technically an overdose (25, 26). The high cost of a single course of uridine triacetate therapy has been cited as a potential barrier to therapy. Nevertheless, 94% of clinical trial individuals treated with uridine triacetate survived the overdose event, a notable improvement over the historic mortality rate of 84% (24).

Symptomatic DPD deficiency is a rare autosomal recessive disorder with a wide range of symptoms, ranging from no symptoms or signs to severe neurological problems. In affected individuals, the absent or greatly reduced DPD activity results in uracil and thymine accumulating in the blood, urine, and cerebrospinal fluid. Neurological symptoms typically manifest in early childhood and include seizures, small head size, and delayed cognitive and motor development (27).

Symptomatic DPD deficiency is typically caused by homozygous inactivation of DPYD; whereas individuals who are heterozygotes tend to be asymptomatic. However, all individuals with less than 70% DPD activity are considered at risk for the development of severe drug toxicity when treated with fluoropyrimidines (28). Signs of capecitabine toxicity include severe diarrhea, severe mucositis, neutropenia, hand-foot syndrome, and neurotoxicity (1).

Capecitabine can cause fetal harm when administered to a pregnant woman; however, the limited human data are not sufficient to inform the drug-associated risk during pregnancy. There is also no information regarding the presence of capecitabine in human milk, or its effects on milk production the breast-fed infant. The FDA label advises that women should not breastfeed during treatment with capecitabine nor for 2 weeks following the final dose. (1)

Safety and efficacy of capecitabine in pediatric individuals has not been established. Additional monitoring and precautions should be employed when administering capecitabine in the elderly and individuals with mild to moderate hepatic dysfunction. Individuals with moderate and severe renal impairment have demonstrated higher exposure for capecitabine and its metabolites when compared to individuals with normal renal function. (1)

## Gene: DPYD

The DPYD gene encodes the enzyme DPD, which catalyzes the first and rate-limiting step in the breakdown of the pyrimidine nucleotides thymine and uracil. Dihydropyrimidine dehydrogenase also catalyzes the rate-limiting step in the breakdown of fluoropyrimidines.

Many DPYD variants have been described, although only a few have been demonstrated to influence DPD enzyme activity. When no variant is detected (formerly known as *1), it is associated with normal enzyme activity. Individuals who have 2 copies of DPYD alleles with normal activity are known as “normal metabolizers” and have fully functional DPD enzyme activity (Table 4). The DPYD alleles c.1601G>A (*4, rs1801158), c.1627G>A (*5, rs1801159), c.2194G>A (*6, rs1801160), and c.85T>C (*9A, rs1801265) are also considered to have normal activity (29). Historically, variant haplotypes in DPYD have been identified by their star (*) allele names. However, the Pharmacogene Variation Database (PharmVar) now identifies these alleles by their dbSNP “rs” allele identifier or cDNA change based on the NM_000110.3 transcript, DPYD mRNA variant 1. All 3 of these identifiers are provided in the Nomenclature for Selected DPYD alleles table below.

Table 4.

Activity Status of Selected DPYD Alleles

Allele type | Alleles
Allele type | Strong evidence to support function | Moderate evidence to support function
Normal function | No variant detected (*1), c.1627G>A (*5, rs1801159), c.85T>C (*9A, rs1801265) | c.1601G>A (*4, rs1801158), c.2194G>A (*6, rs1801160), c.1003G>T (*11, rs72549306), c.2657G>A (*9B, rs1801267), 496A>G (rs2297595)
Decreased function | c.2846A>T (rs67376798), 1129-5923C>G and 1236G>A (HapB3) | c.557A>G (rs115232898)
No function | c.1905+1G>A (*2A, rs3918290) | c.1898delC (*3, rs72549303), c.295_298delTCAT (*7, rs72549309), c.703C>T (*8, rs1801266), c.2983G>T (*10, rs1801268), c.1156G>T (*12), c.1679T>G (*13, rs55886062)

This table is adapted from the “DPYD Allele Functionality Table”, available from CPIC (https://cpicpgx.org/guidelines/guideline-for-fluoropyrimidines-and-dpyd/). Additional variant information from the PharmVar (https://www.pharmvar.org/gene/DPYD) database. cDNA coordinates for variation are given for NM_000110.3, DPYD transcript variant 1.

For the nomenclature of human DPYD alleles, please see (30).

The nonfunctional DPYD variants that have been associated with absent DPD activity and an increased risk of toxicity with fluoropyrimidines include c.1905+1G>A (*2A, rs3918290) and c.1679T>G (*13, rs55886062) (22). Variants with decreased function include rs67376798 (c.2846A>T) and HapB3, which also are associated with an increased risk of fluoropyrimidine toxicity. The most well-studied variant is DPYD c.1905+1G>A (*2A, rs3918290), in which a single nucleotide substitution at the invariant splice donor site of intron 14 leads to exon 14 skipping, resulting in the production of a truncated protein with no enzyme activity.

Individuals who have one normal function and one decreased function or no function DPYD alleles are known as “intermediate metabolizers”. Individuals with 2 decreased function alleles are also categorized as intermediate metabolizers, as they have partial DPD deficiency and are at increased risk of capecitabine toxicity. And individuals who have a combination of nonfunctional DPYD alleles, or decreased function DPYD alleles, or both are known as “poor metabolizers”, as they have complete DPD deficiency and are at very high risk of capecitabine toxicity.

Activity scores may be used to distinguish between the various DPYD alleles and their functionality (Table 5). The use of activity scores may result in differentiated individualized dosing advice for fluoropyrimidines, which is beneficial for reducing toxic side effects while maintaining efficacy (16).

Table 5.

Assignment of likely DPD Phenotype based on DPYD Genotype (CPIC, 2017)

Likely phenotype | Activity score^a^ | Genotype^b^ | Examples of genotype^c^
DPYD normal metabolizer | 2 | An individual with 2 normal function alleles. | c.[=]; [=] c.[85T>C]; [=] c.[1627A>G]; [=]
DPYD intermediate metabolizer (approximately 3–5% of individuals) | 1 or 1.5 | An individual with one normal function allele plus one no function allele or one decreased function allele, or an individual with 2 decreased function alleles. | c.[1905+1G>A]; [=] c.[1679T>G]; [=] c.[2846A>T]; [=] c.[1129–5923C>G]; [=]^d^ c.[1129–5923C>G]; [1129–5923C>G]^d^ c.[2846A>T]; [2846A>T]
DPYD poor metabolizer (approximately 0.2% of individuals) | 0 or 0.5 | An individual with 2 no function alleles or an individual with one no function plus one decreased function allele. | c.[1905+1G>A]; [1905+1G>A] c.[1679T>G]; [1679T>G] c.[1905+1G>A]; [2846A>T] c.[1905+1G>A]; [1129-5923C>G]

"[ ]" Square brackets are used to indicate an allele, "[=]" Indicates the allele sequence was tested and no changes were found

^a^ Calculated as the sum of the 2 lowest individual variant activity scores. See (2) for further information.

^b^ Allele definitions, assignment of allele function and references can be found on the CPIC website (https://cpicpgx.org/guidelines/guideline-for-fluoropyrimidines-and-dpyd/) (DPYD Allele Functionality Table)

^c^ HGVS nomenclature using the reference sequence NM_000110.3.

^d^ Likely HapB3 causal variant. See DPYD Allele Functionality Table available or other HapB3 proxy SNPs. This table is adapted from (2).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Note: The nomenclature used in this table reflects the standardized nomenclature for pharmacogenetic terms proposed by CPIC (6).

Overall, the prevalence of individuals who are heterozygous for nonfunctional variant DPYD alleles (partially DPD deficient) and at risk of severe drug reactions is estimated to be as high as 5–8%, but this varies in different populations (9, 28, 31, 32, 33, 34, 35). In Caucasians, approximately 3–5% of have partial DPD deficiency and 0.2% have complete DPD deficiency (32). Recent studies suggest that ~8% of Caucasians have at least one of the 4 best-known altered-function alleles (36).

In African-Americans, the prevalence of decreased DPD enzyme activity is 8% (35). It is notable that despite being well studied, DPYD c.1905+1G>A (*2A, rs3918290) is very rare in individuals of African ancestry (37). One study did note that the normal function c.85T>C (*9A, rs1801265) variant was present in 49% of African-American samples (38). The rs115232898 (c.557A>G) variant allele with reduced function was detected in 2.6% of African-heritage Brazilians (39).

Studies of Egyptian and Tunisian populations suggest the allelic frequencies for DPYD variants in in these 2 countries are similar to Caucasian variant allele frequencies (40, 41). The frequency of the poor-metabolizer rs67376798 (c.2846A>T) allele in Mestizo and Native Mexican populations is rare, but not significantly different than in MXL (Mexican Ancestry from Los Angeles USA) or CEU (Utah Residents (CEPH) with Northern and Western European Ancestry) populations in the 1000 genomes project (42).

Asian populations have slightly different allele frequencies as compared to African and European populations. The frequency of the c.85T>C (*9A, rs1801265) normal function variant was slightly lower in Han Chinese, Korean and Japanese populations, particularly compared to Africans, though the frequency of the c.2657G>A (*9B, rs1801267) normal function variant and c.295_298delTCAT (*7, rs72549309), c.703C>T (*8, rs1801266), and c.2983G>T (*10, rs1801268) no function alleles were similar across these groups (38). The c.1905+1G>A (*2A/*2B, rs3918290) and c.1679T>G (*13, rs55886062) no function alleles were not detected in a study of Hmong and East Asian descent individuals, underscoring the rarity of these alleles (43). An analysis of multiple genotyping studies in South Asian populations found that the normal function rs2297595 (c.496A>G) allele was prevalent in south Asia (44).

Most individuals in the US are not screened for DPD deficiency before starting fluorouracil therapy (45). In contrast, the European Medicines Agency recommends testing for DPD deficiency before initiating treatment with any fluorouracil related chemotherapy (46).

## Gene: TYMS

Emerging studies and reports suggest that genetic variation at another locus may also affect 5-FU efficacy and toxicity—TYMS. This gene encodes TS, which catalyzes the methylation of deoxyuridylate to deoxythymidylate. This reaction is a rate-limiting step in the production of an essential DNA synthesis precursor. The TS expression correlates with sensitivity to 5-FU and the TS enzyme one of the targets of 5-FU(47). While this functional link to 5-FU metabolism and tumor response has been demonstrated in multiple studies, the impact of specific genetic variants in TYMS is less clear (47, 48, 49, 50). The TYMS alleles have been reported in a handful of studies as being associated with increased toxicity and anti-tumor cell response with fluoropyrimidines.

The rs45445694 polymorphism is the defining variant of the TYMS “2R” allele, which has been associated with clinical response and severe toxicity events, either in homozygosity or heterozygosity (25, 51, 52, 53). This allele is in the 5’UTR and is a duplication a 28 base pair (bp) repeat. This same locus can have variable tandem repeats between 0 and 9 copies, and studies suggest that increased copy numbers of the repeat are associated with increased TYMS expression and TS protein levels (54).

One additional variant in TYMS has been found in association with adverse reactions to fluoropyrimidine therapy: a 3'UTR 9 bp-indel (rs11280056) (52, 54). There are conflicting reports as to whether this is a 6- or 9-bp-indel. One variant (rs2853542) within the TYMS enhancer region in the context of the 28bp tandem repeat triplication, called 3RG or 3RC based on the specific nucleotide present, has also been reported in association with neurotoxicity during 5-FU treatment (55). The presence of the C nucleotide at rs2853542 has been associated with decreased expression of TYMS mRNA (56).

PharmGKB has described TYMS as a Very Important Pharmacogene, though the level of evidence for TYMS and capecitabine/5-fluorouracil interaction is limited (PharmGKB “level 3”) (54). CPIC also views this interaction as having limited evidence and thus provides no prescribing recommendations for these pharmacogenetic variants (57).

## Linking Gene Variation with Treatment Response

Standard doses of fluorouracil increase the risk of severe toxicity in individuals who have specific DPYD variant alleles. No dose of capecitabine is safe in individuals with absent DPD activity (1, 36). Multiple studies have found that preemptive DPYD screening for individuals with cancer can significantly improve individual safety (10, 58, 59, 60, 61, 62, 63, 64). Additionally, prospective genotyping decreased chemotherapy toxicities and was cost effective (10).

At least one case report indicated that the cost of administering uridine triacetate and palliative care following an adverse, overdose reaction to 5-FU was roughly $180,000 USD (25). This is significantly higher than the cost of most pre-emptive pharmacogenetic tests.

## Genetic Testing

The NIH Genetic Testing Registry, GTR, displays genetic tests that are available for the DPYD gene (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1806%5Bgeneid%5D), TYMS gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=7298%5bgeneid%5d), and the capecitabine drug response (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN077963%5BDISCUI%5D). The DPYD*2A variant is the most commonly tested. Tests available for clinical practice include full gene sequencing and targeted panel-based testing of selected variants. In cases where a targeted panel is used, only those specific variants are examined, A negative result does not mean the individual does not have DPD deficiency. Clinicians should refer to the specific testing laboratory for complete information on the test. CPIC provides a table of minor allele frequencies for DPYD variants per ethnic populations, which may be useful when determining what type of test or panel will be most informative for any individual (5).

Biochemical genetic tests may also be used, which assess the level of activity of the DPD enzyme. These tests include biochemical assays such as analyte testing (for example, measuring the amount of thymine and uracil in the urine or blood) or an enzyme assay (for example, directly measuring the activity of DPD using RNA extracted from blood cells and measuring the DPD mRNA copy number) (46, 65, 66).

The GTR provides a list of biochemical tests that assess the levels of thymine (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=thymine&filter=method:1_1) and uracil (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=uracyl&filter=method:1_1) analytes, and the activity of the enzyme dihydropyrimidine dehydrogenase (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=dihydropyrimidine%20dehydrogenase&filter=method:1_2).

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2020 Statement from the US Food and Drug Administration (FDA)

Based on postmarketing reports, individuals with certain homozygous or certain compound heterozygous mutations in the [DPYD] gene that result in complete or near complete absence of DPD activity are at increased risk for acute early-onset of toxicity and severe, life-threatening, or fatal adverse reactions caused by capecitabine (e.g., mucositis, diarrhea, neutropenia, and neurotoxicity). Individuals with partial DPD activity may also have increased risk of severe, life-threatening, or fatal adverse reactions caused by capecitabine.

Withhold or permanently discontinue capecitabine based on clinical assessment of the onset, duration and severity of the observed toxicities in individuals with evidence of acute early-onset or unusually severe toxicity, which may indicate near complete or total absence of DPD activity. No capecitabine dose has been proven safe for individuals with complete absence of DPD activity. There is insufficient data to recommend a specific dose in individuals with partial DPD activity as measured by any specific test.

Please review the complete therapeutic recommendations that are located here: (1).

### 2017 Statement from the Clinical Pharmacogenetics Implementation Consortium (CPIC), with November 2018 Update

[…]

Table 2 summarizes the genetics-based dosing recommendations for fluoropyrimidines using the calculated DPYD activity score (DPYD-AS). The strength of the prescribing recommendations is based on the known impact of some variants (c.1905+1G>A, c.1679T>G, c.2846A>T, c.1129–5923C>G) on DPD activity, the demonstrated relationship between DPD activity and 5- fluorouracil clearance, and between 5-fluorouracil exposure and its toxic effects. Individuals who are heterozygous for DPYD decreased/no function variants demonstrate partial DPD deficiency and should receive reduced starting doses. Prospective genotyping of c.1905+1G>A followed by a 50% dose reduction in heterozygous carriers resulted in a rate of severe toxicity comparable to noncarriers[see (10)]. This study thus demonstrated that DPYD genetic testing can reduce the occurrence of severe fluoropyrimidine-related toxicity, and that a dose reduction of 50% is suitable for heterozygous carriers of no function variants (DPYD-AS: 1). For decreased function variants, evidence is limited regarding the optimal degree of dose reduction. For c.2846A>T, a small retrospective study observed that the average capecitabine dose in heterozygous carriers was reduced by 25% compared to noncarriers. In a small prospective study, five individuals carrying c.1236G>A (proxy for c.1129–5923C>G) were safely treated with a 25% reduced capecitabine starting dose. This suggests that heterozygous carriers of decreased function variants (DPYD-AS: 1.5) may tolerate higher doses com- pared to carriers of no function variants (DPYD-AS: 1). In individuals with DPYD-AS of 1.5, the individual circumstances of a given individual should therefore be considered to determine if a more cautious approach (50% starting dose followed by dose titration), or an approach maximizing potential effectiveness with a potentially higher toxicity risk (25% dose reduction) is preferable. Of note, both studies indicating the suitability of a 25% dose reduction in decreased function variant carriers included only individuals receiving capecitabine and no data are currently available for infusional 5-fluorouracil.

Given that some individuals carrying decreased or no function variants tolerate normal doses of 5-fluorouracil, to maintain effectiveness, doses should be increased in subsequent cycles in individuals experiencing no or clinically tolerable toxicity in the first two chemotherapy cycles or with subtherapeutic plasma concentrations. Similarly, doses should be decreased in individuals who do not tolerate the starting dose.

In DPYD poor metabolizers (DPYD-AS: 0.5 or 0), it is strongly recommended to avoid use of 5-fluorouracil-containing regimens. However, if no fluoropyrimidine-free regimens are considered a suitable therapeutic option, 5-fluorouracil administration at a strongly reduced dose combined with early therapeutic drug monitoring may be considered for individuals with DPYD-AS of 0.5. It should be noted, however, that no reports of the successful administration of low-dose 5-fluorouracil in DPYD poor metabolizers are available to date. Assuming additive effects of decreased and no function alleles (DPYD-AS: 0.5), it is estimated that a dose reduction of at least 75% would be required (i.e., starting dose <25% of normal dose). Furthermore, in such cases a phenotyping test is advisable to estimate DPD activity and a starting dose.

The US Food and Drug Administration (FDA) and the Health Canada Santé Canada (HCSC) have added statements to the drug labels for 5-fluorouracil and capecitabine that warn against use in individuals with DPD deficiency, and prescribing recommendations for 5-fluorouracil, capecitabine, and tegafur are also available from the Dutch Pharmacogenetics Working Group.

November 2018 Update:

The current DPYD guideline recommends to reduce the dose of fluoropyrimidines by 25-50% (from the full standard dose) in DPYD Intermediate Metabolizers with an activity score of 1.5. At the time of the guideline publication, this dose range was recommended due to limited evidence for genotype-guided dosing of decreased function alleles/variants. However, a recent prospective study (PMID: 30348537) provides evidence to support a recommendation for a 50% dose reduction in heterozygous carriers of the decreased function variants c.2846A>T (rs67376798) or c.1129–5923C>G (rs75017182; HapB3 or its tagging variant c.1236G>A; rs56038477). These data suggest that all Intermediate Metabolizers with an activity score of 1.5 should receive a 50% dose reduction.

Therefore CPIC revises its recommendation such that all DPYD Intermediate Metabolizers should receive a 50% dose reduction from the full standard starting dose, whether the activity score is 1 or 1.5 followed by dose titration, based on clinical judgement and ideally therapeutic drug monitoring.

In addition, recent case reports from individuals who are homozygous for c.2846A>T (activity score of 1) indicate that a dose reduction of more than 50% may be required in some carriers of this genotype. Therefore, in individuals with an activity score of 1 due to a homozygous c.[2846A>T];[2846A>T] genotype, clinicians should be aware that a >50% reduction in starting dose might be warranted.

Please review the complete therapeutic recommendations that are located here: (2, 5)

### 2019 Summary of recommendations from the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

DPD Gene Activity Score 0

The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the standard dose is a more than 100-fold overdose.

- Avoid fluorouracil and capecitabine

Tegafur is not an alternative, as this is also metabolized by DPD.

- If it is not possible to avoid fluorouracil and capecitabine: determine the residual DPD activity in mononuclear cells from peripheral blood and adjust the initial dose accordingly.

An individual with 0.5% of the normal DPD activity tolerated 0.8% of the standard dose (150 mg capecitabine every 5 days). An individual with undetectable DPD activity tolerated 0.43% of the standard dose (150 mg capecitabine every 5 days with every third dose skipped)

DPD PHENO [phenotyping indicates reduced function]

The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.

It is not possible to recommend a dose adjustment for this individual based on the genotype only.

- determine the residual DPD activity in mononuclear cells from peripheral blood and adjust the initial dose based on phenotype and genotype, or avoid fluorouracil and capecitabine.

Tegafur is not an alternative, as this is also metabolized by DPD.

DPD Gene Activity Score 1

The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.

- Start with 50% of the standard dose or avoid fluorouracil and capecitabine.

Adjustment of the subsequent dose should be guided by toxicity and effectiveness. However, in one study involving 17 individuals with gene activity 1, the average dose after titration was 57% of the standard dose.

Tegafur is not an alternative, as this is also metabolized by DPD.

DPD Gene Activity Score 1.5

The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.

- Start with 50% of the standard dose or avoid fluorouracil and capecitabine.

After starting treatment, the dose should be adjusted based on toxicity and effectiveness. In a study involving 17 individuals with genotype 1/2846T, the average dose after titration was 64% of the standard dose. For 51 individuals with genotype 1/1236A, the average dose after titration was 74% of the standard dose. Tegafur is not an alternative, as this is also metabolized by DPD.

DPD Gene Activity Score 0 (Cutaneous fluorouracil)

The gene variation increases the risk of severe, potentially fatal toxicity. A reduced conversion of fluorouracil/capecitabine to inactive metabolites means that the normal dose is an overdose.

- avoid fluorouracil

NOTE: If an individual has two different genetic variations that lead to a non-functional DPD enzyme (e.g. *2A and *13), this recommendation only applies if the variations are on a different allele. If both variations are on the same allele, this individual actually has a gene activity score 1, for which no increased risk of severe, potentially fatal toxicity has been found with cutaneous use. These two situations can only be distinguished by determining the enzyme activity (phenotyping). This recommendation only applies if the individual has virtually no enzyme activity.

Background Information - Mechanism

Fluorouracil is mainly (> 80%) converted by dihydropyrimidine dehydrogenase (DPD) to inactive metabolites. Lower metabolic activity of DPD leads to increased intracellular concentrations of fluorodeoxyuridine monophosphate, the active metabolite of fluorouracil and its prodrug capecitabine. This leads to an increased risk of adverse events such as neutropenia, thrombopenia and hand-foot syndrome.

For more information about the phenotype gene activity score: see the general background information about DPD on the KNMP Knowledge Bank or on www.knmp.nl (search for DPD).

Please review the complete therapeutic recommendations that are located here: (3, 4).

## Nomenclature for Selected DPYD Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
rs3918290 | DPYD*2A, c.1905+1G>A | NM_000110.3:c.1905+1G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/432/) | Not applicable—deletion of exon 14 leads to the production of a truncated protein | rs3918290 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=rs3918290)
rs3918290 | IVS14+1G>A | NM_000110.3:c.1905+1G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/432/) | Not applicable—deletion of exon 14 leads to the production of a truncated protein | rs3918290 (http://www.ncbi.nlm.nih.gov/SNP/snp_ref.cgi?rs=rs3918290)
rs55886062 | DPYD*13, c.1679T>G, rs55886062.1, p.Ile560Ser | NM_000110.3:c.1679T>G (http://www.ncbi.nlm.nih.gov/clinvar/variation/88975/) | NP_000101.2:p.Ile560Ser (http://www.ncbi.nlm.nih.gov/clinvar/variation/88975/) | rs55886062 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=55886062)
rs67376798 | c.2846A>T p.Asp949Val | NM_000110.3:c.2846A>T (http://www.ncbi.nlm.nih.gov/clinvar/variation/88974/) | NP_000101.2:p.Asp949Val (http://www.ncbi.nlm.nih.gov/clinvar/variation/88974/) | rs67376798 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=67376798)
rs75017182 | c.1129–5923C>G | NM_000110.3:c.1129-5923C>G (https://www.ncbi.nlm.nih.gov/clinvar/47766551/) | Altered mRNA splicing introduces premature termination codon in resulting protein. | rs75017182 (http://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=75017182)
rs1801159 | DPYD*5, c.1627G>A | NM_000110.4:c.1627A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/100092/) | NP_000101.2:p.Ile543Val (https://www.ncbi.nlm.nih.gov/clinvar/variation/100092/) | rs1801159 (https://www.ncbi.nlm.nih.gov/snp/rs1801159)
rs1801265 | DPYD*9A, c.85T>C | NM_000110.4:c.85T>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/100123/) | NP_000101.2:p.Cys29Arg (https://www.ncbi.nlm.nih.gov/clinvar/variation/100123/) | rs1801265 (https://www.ncbi.nlm.nih.gov/snp/rs1801265)
rs1801158 | DPYD*4, c.1601G>A | NM_000110.4:c.1601G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/100094/) | NP_000101.2:p.Ser534Asn (https://www.ncbi.nlm.nih.gov/clinvar/variation/100094/) | rs1801158 (https://www.ncbi.nlm.nih.gov/snp/rs1801158)
rs1801160 | DPYD*6, c.2194G>A | NM_000110.4:c.2194G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/100080/) | NP_000101.2:p.Val732Ile (https://www.ncbi.nlm.nih.gov/clinvar/variation/100080/) | rs1801160 (https://www.ncbi.nlm.nih.gov/snp/rs1801160)
rs72549306 | DPYD*11, c.1003G>T, rs72549306.1 | NM_000110.4:c.1003G>T | NP_000101.2:p.Val335Leu | rs72549306 (https://www.ncbi.nlm.nih.gov/snp/rs72549306)
rs1801267 | DPYD*9B, c.2657G>A | NM_000110.4:c.2657G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/437/) | NP_000101.2:p.Arg886His (https://www.ncbi.nlm.nih.gov/clinvar/variation/437/) | rs1801267 (https://www.ncbi.nlm.nih.gov/snp/rs1801267)
rs72549303 | DPYD*3, c.1898delC | NM_000110.4:c.1898del (https://www.ncbi.nlm.nih.gov/clinvar/variation/635266/) | NP_000101.2:p.Pro633fs (https://www.ncbi.nlm.nih.gov/clinvar/variation/635266/) | rs72549303 (https://www.ncbi.nlm.nih.gov/snp/rs72549303)
rs72549309 | DPYD*7, c.295_298delTCAT | NM_000110.4:c.295_298TCAT[1] (https://www.ncbi.nlm.nih.gov/clinvar/variation/495550/) | NP_000101.2:p.Phe100fs (https://www.ncbi.nlm.nih.gov/clinvar/variation/495550/) | rs72549309 (https://www.ncbi.nlm.nih.gov/snp/rs72549309)
rs1801266 | DPYD*8, c.703C>T | NM_000110.4:c.703C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/298300/) | NP_000101.2:p.Arg235Trp (https://www.ncbi.nlm.nih.gov/clinvar/variation/298300/) | rs1801266 (https://www.ncbi.nlm.nih.gov/snp/rs1801266)
rs1801268 | DPYD*10, c.2983G>T | NM_000110.4:c.2983G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/635267/) | NP_000101.2:p.Val995Phe (https://www.ncbi.nlm.nih.gov/clinvar/variation/635267/) | rs1801268 (https://www.ncbi.nlm.nih.gov/snp/rs1801268)
rs78060119 | DPYD*12, c.1156G>T | NM_000110.4:c.1156G>T | NP_000101.2:p.Glu386Ter | rs78060119 (https://www.ncbi.nlm.nih.gov/snp/rs78060119)
rs115232898 | 557A>G (Y186C) | NM_000110.4:c.557A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/100113/) | NP_000101.2:p.Tyr186Cys (https://www.ncbi.nlm.nih.gov/clinvar/variation/100113/) | rs115232898 (https://www.ncbi.nlm.nih.gov/snp/rs115232898)
rs2297595 | 496A>G (M166V) | NM_000110.4:c.496A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/100116/) | NP_000101.2:p.Met166Val (https://www.ncbi.nlm.nih.gov/clinvar/variation/100116/) | rs2297595 (https://www.ncbi.nlm.nih.gov/snp/rs2297595)
rs75017182 rs56038477 | HapB3 1129-5923C>G 1236G>A | NM_000110.4:c.1129-5923C>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/635263/) NM_000110.4:c.1236G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/100100/) | Altered mRNA splicing introduces premature termination codon in resulting protein. NP_000101.2:p.Glu412= | rs75017182 (https://www.ncbi.nlm.nih.gov/snp/rs75017182) rs56038477 (https://www.ncbi.nlm.nih.gov/snp/rs56038477)
rs45445694 | 2R, 3R TYMS 5’UTR | GRCh37.p13 chr 18, NC_000018.9:g.657657_657712del, NC_000018.9:g.657657_657684GGCCTGCCTCCGTCCCGCCGCGCCACTT[1]-[9]^#^ | | rs45445694 (https://www.ncbi.nlm.nih.gov/snp/rs45445694)
rs11280056 | TYMS 3’UTR | GRCh37.p13 chr 18, NC_000018.9:g.673447_673452del, NC_000018.9:g.673447_673452dup^#^ NM_017512.7:c.*856_*861del (https://www.ncbi.nlm.nih.gov/clinvar/variation/375663/) | | rs11280056 (https://www.ncbi.nlm.nih.gov/snp/rs11280056)
rs2853542 | TYMS 3RG, 3RC | GRCh37.p13 chr 18, NC_000018.9:g.657685G>C^#^ NM_001071.4:c.-58= | | rs2853542 (https://www.ncbi.nlm.nih.gov/snp/rs2853542)

# This is a non-coding variant in the TYMS untranslated region. Coordinates given are chromosomal.

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (13).

Allele information for DPYD can also be found at the Pharmacogene Variation Consortium (PharmVar (https://www.pharmvar.org/gene/DPYD)).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

## Acknowledgments

The authors would like to thank Peter H. O’Donnell, MD, Associate Professor of Medicine, Section of Hematology/Oncology, Department of Medicine, Deputy Director, Center for Personalized Therapeutics, Committee on Clinical Pharmacology and Pharmacogenomics, The University of Chicago, Chicago, IL, USA; Natalie Reizine, MD, Hematology and Oncology Fellow, Clinical Pharmacology and Pharmacogenomics Fellow, University of Chicago Medicine, Chicago, IL, USA; and Chara Stavraka, MD, MRCP, PhD, NIHR Academic Clinical Fellow & Specialist Registrar in Medical Oncology, King’s College London/Guy's and St Thomas' NHS Foundation Trust, London, UK for reviewing this summary.

2016 Edition

The author would like to thank Linda Henricks, PharmD, and Professor Jan HM Schellens, MD PhD, The Netherlands Cancer Institute, Amsterdam, The Netherlands; Mohamed Nagy, Clinical Pharmacist, Head of the Personalised Medication Management Unit, Department of Pharmaceutical Services, Children's Cancer Hospital, Cairo, Egypt; and Emily K. Pauli, Director of Research, Clearview Cancer Institute, Huntsville, AL, USA for reviewing this summary.

## Version history

A minor revision to this summary was made on 14 August 2025 to update the URL for a citation.

To view the 2016 version of this summary (created on 15 September 2016) please click here.

## References

1 CAPECITABINE- capecitabine tablet, film coated [package insert]. Indiana, US: ArevaPharmaceuticals; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=9ec7f840-e746-ded8-e053-2995a90ab3a2.
2 Amstutz, U., L.M. Henricks, S.M. Offer, J. Barbarino, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for Dihydropyrimidine Dehydrogenase Genotype and Fluoropyrimidine Dosing: 2017 Update. Clin Pharmacol Ther, 2018. 103(2): p. 210-216.29152729
3 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. DPD- 5-fluoruracil/capecitabine [Cited 2020]. Available from https://www.knmp.nl/dossiers/farmacogenetica.
4 Lunenburg, C., C.H. van der Wouden, M. Nijenhuis, M.H. Crommentuijn-van Rhenen, et al., Dutch Pharmacogenetics Working Group (DPWG) guideline for the gene-drug interaction of DPYD and fluoropyrimidines. Eur J Hum Genet, 2020. 28(4): p. 508-517.31745289
5 CPIC Guidelines for Fluoropyrimidines and DPYD. 2020 February 2020 27 August 2020]; Available from: https://cpicpgx.org/guidelines/guideline-for-fluoropyrimidines-and-dpyd/.
6 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215-223.27441996
7 Wilson, P.M., P.V. Danenberg, P.G. Johnston, H.J. Lenz, and R.D. Ladner, Standing the test of time: targeting thymidylate biosynthesis in cancer therapy. Nat Rev Clin Oncol, 2014. 11(5): p. 282-98.24732946
8 FLUOROURACIL - fluorouracil injection, solution [package insert]. Illinois, USA: FreseniusKabi; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=c45f5286-a52b-43e5-8a6f-d0312e7da0c8.
9 Amstutz, U., S. Farese, S. Aebi, and C.R. Largiader, Dihydropyrimidine dehydrogenase gene variation and severe 5-fluorouracil toxicity: a haplotype assessment. Pharmacogenomics, 2009. 10(6): p. 931-44.19530960
10 Deenen, M.J., D. Meulendijks, A. Cats, M.K. Sechterberger, et al., Upfront Genotyping of DPYD*2A to Individualize Fluoropyrimidine Therapy: A Safety and Cost Analysis. J Clin Oncol, 2016. 34(3): p. 227-34.26573078
11 Boige, V., M. Vincent, P. Alexandre, S. Tejpar, et al., DPYD Genotyping to Predict Adverse Events Following Treatment With Flourouracil-Based Adjuvant Chemotherapy in Patients With Stage III Colon Cancer: A Secondary Analysis of the PETACC-8 Randomized Clinical Trial. JAMA Oncol, 2016.
12 Raida, M., W. Schwabe, P. Hausler, A.B. Van Kuilenburg, et al., Prevalence of a common point mutation in the dihydropyrimidine dehydrogenase (DPD) gene within the 5'-splice donor site of intron 14 in patients with severe 5-fluorouracil (5-FU)- related toxicity compared with controls. Clinical cancer research : an official journal of the American Association for Cancer Research, 2001. 7(9): p. 2832-9.11555601
13 Kalman, L.V., J. Agundez, M.L. Appell, J.L. Black, et al., Pharmacogenetic allele nomenclature: International workgroup recommendations for test result reporting. Clin Pharmacol Ther, 2016. 99(2): p. 172-85.26479518
14 Lee, A.M., Q. Shi, E. Pavey, S.R. Alberts, et al., DPYD variants as predictors of 5-fluorouracil toxicity in adjuvant colon cancer treatment (NCCTG N0147). J Natl Cancer Inst, 2014. 106(12).25381393
15 Gentile, G., A. Botticelli, L. Lionetto, F. Mazzuca, et al., Genotype-phenotype correlations in 5-fluorouracil metabolism: a candidate DPYD haplotype to improve toxicity prediction. Pharmacogenomics J, 2016. 16(4): p. 320-5.26216193
16 Henricks, L.M., C.A. Lunenburg, D. Meulendijks, H. Gelderblom, et al., Translating DPYD genotype into DPD phenotype: using the DPYD gene activity score. Pharmacogenomics, 2015. 16(11): p. 1277-86.26265346
17 Toffoli, G., L. Giodini, A. Buonadonna, M. Berretta, et al., Clinical validity of a DPYD-based pharmacogenetic test to predict severe toxicity to fluoropyrimidines. Int J Cancer, 2015. 137(12): p. 2971-80.26099996
18 Megdanova-Chipeva, V.G., A. Lamarca, A. Backen, M.G. McNamara, et al., Systemic Treatment Selection for Patients with Advanced Pancreatic Neuroendocrine Tumours (PanNETs). Cancers (Basel), 2020. 12(7).32708210
19 Kamarajah, S.K., J.R. Bundred, W. Alrawashdeh, D. Manas, and S.A. White, A systematic review and network meta-analysis of phase III randomised controlled trials for adjuvant therapy following resection of pancreatic ductal adenocarcinoma (PDAC). HPB (Oxford), 2020. 22(5): p. 649-659.31894014
20 Rogers, J.E., L. Xiao, A. Trail, M. Blum Murphy, et al., Nivolumab in Combination with Irinotecan and 5-Fluorouracil (FOLFIRI) for Refractory Advanced Gastroesophageal Cancer. Oncology, 2020. 98(5): p. 289-294.32097933
21 Fulcher, C.D., M. Haigentz, Jr., T.J. Ow, H. Education Committee of the American, and S. Neck, AHNS Series: Do you know your guidelines? Principles of treatment for locally advanced or unresectable head and neck squamous cell carcinoma. Head Neck, 2018. 40(4): p. 676-686.29171929
22 Deenen, M.J., J. Tol, A.M. Burylo, V.D. Doodeman, et al., Relationship between single nucleotide polymorphisms and haplotypes in DPYD and toxicity and efficacy of capecitabine in advanced colorectal cancer. Clinical cancer research : an official journal of the American Association for Cancer Research, 2011. 17(10): p. 3455-68.21498394
23 Drug Trials Snapshots: VISTOGARD. 2020 20 August 2020; Available from: https://web.archive.org/web/20221126234744/https://www.fda.gov/drugs/drug-approvals-and-databases/drug-trials-snapshots-vistogard
24 Ma, W.W., M.W. Saif, B.F. El-Rayes, M.G. Fakih, et al., Emergency use of uridine triacetate for the prevention and treatment of life-threatening 5-fluorouracil and capecitabine toxicity. Cancer, 2017. 123(2): p. 345-356.27622829
25 Baldeo, C., P. Vishnu, K. Mody, and P.M. Kasi, Uridine triacetate for severe 5-fluorouracil toxicity in a patient with thymidylate synthase gene variation: Potential pharmacogenomic implications. SAGE Open Med Case Rep, 2018. 6: p. 2050313X18786405.
26 Velez-Velez, L.M., C.L. Hughes, and P.M. Kasi, Clinical Value of Pharmacogenomic Testing in a Patient Receiving FOLFIRINOX for Pancreatic Adenocarcinoma. Front Pharmacol, 2018. 9: p. 1309.30498448
27 Al-Sanna'a, N.A., A.B. Van Kuilenburg, T.M. Atrak, M.A. Abdul-Jabbar, and A.H. Van Gennip, Dihydropyrimidine dehydrogenase deficiency presenting at birth. J Inherit Metab Dis, 2005. 28(5): p. 793-6.16151913
28 Van Kuilenburg, A.B., P. Vreken, N.G. Abeling, H.D. Bakker, et al., Genotype and phenotype in patients with dihydropyrimidine dehydrogenase deficiency. Hum Genet, 1999. 104(1): p. 1-9.10071185
29 Offer, S.M., C.C. Fossum, N.J. Wegner, A.J. Stuflesser, et al., Comparative functional analysis of DPYD variants of potential clinical relevance to dihydropyrimidine dehydrogenase activity. Cancer Res, 2014. 74(9): p. 2545-54.24648345
30 McLeod, H.L., E.S. Collie-Duguid, P. Vreken, M.R. Johnson, et al., Nomenclature for human DPYD alleles. Pharmacogenetics, 1998. 8(6): p. 455-9.9918128
31 Saif, M.W., H. Ezzeldin, K. Vance, S. Sellers, and R.B. Diasio, DPYD*2A mutation: the most common mutation associated with DPD deficiency. Cancer chemotherapy and pharmacology, 2007. 60(4): p. 503-7.17165084
32 Morel, A., M. Boisdron-Celle, L. Fey, P. Soulie, et al., Clinical relevance of different dihydropyrimidine dehydrogenase gene single nucleotide polymorphisms on 5-fluorouracil tolerance. Molecular cancer therapeutics, 2006. 5(11): p. 2895-904.17121937
33 Gonzalez, F.J. and P. Fernandez-Salguero, Diagnostic analysis, clinical importance and molecular basis of dihydropyrimidine dehydrogenase deficiency. Trends in pharmacological sciences, 1995. 16(10): p. 325-7.7491709
34 Lee, A., H. Ezzeldin, J. Fourie, and R. Diasio, Dihydropyrimidine dehydrogenase deficiency: impact of pharmacogenetics on 5-fluorouracil therapy. Clinical advances in hematology & oncology : H&O, 2004. 2(8): p. 527-32.
35 Mattison, L.K., J. Fourie, R.A. Desmond, A. Modak, et al., Increased prevalence of dihydropyrimidine dehydrogenase deficiency in African-Americans compared with Caucasians. Clin Cancer Res, 2006. 12(18): p. 5491-5.17000684
36 Lunenburg, C., L.M. Henricks, E. Dreussi, F.P. Peters, et al., Standard fluoropyrimidine dosages in chemoradiation therapy result in an increased risk of severe toxicity in DPYD variant allele carriers. Eur J Cancer, 2018. 104: p. 210-218.30361102
37 Elraiyah, T., C.R. Jerde, S. Shrestha, R. Wu, et al., Novel Deleterious Dihydropyrimidine Dehydrogenase Variants May Contribute to 5-Fluorouracil Sensitivity in an East African Population. Clin Pharmacol Ther, 2017. 101(3): p. 382-390.27727460
38 Shin, J.G., H.S. Cheong, J.Y. Kim, L.H. Kim, et al., Screening of dihydropyrimidine dehydrogenase genetic variants by direct sequencing in different ethnic groups. J Korean Med Sci, 2013. 28(8): p. 1129-33.23960437
39 Cunha-Junior, G.F., L. Bastos-Rodrigues, P.G. Azevedo, M.A. Bicalho, et al., Prevalence of the DPYD variant (Y186C) in Brazilian individuals of African ancestry. Cancer Chemother Pharmacol, 2019. 84(6): p. 1359-1363.31641844
40 Ben Fredj, R., E. Gross, L. Chouchen, F. B'Chir, et al., Mutational spectrum of dihydropyrimidine dehydrogenase gene (DPYD) in the Tunisian population. C R Biol, 2007. 330(10): p. 764-9.17905396
41 Hamdy, S.I., M. Hiratsuka, K. Narahara, M. El-Enany, et al., Allele and genotype frequencies of polymorphic cytochromes P450 (CYP2C9, CYP2C19, CYP2E1) and dihydropyrimidine dehydrogenase (DPYD) in the Egyptian population. Br J Clin Pharmacol, 2002. 53(6): p. 596-603.12047484
42 Gonzalez-Covarrubias, V., M. Morales-Franco, O.F. Cruz-Correa, A. Martinez-Hernandez, et al., Variation in Actionable Pharmacogenetic Markers in Natives and Mestizos From Mexico. Front Pharmacol, 2019. 10: p. 1169.31649539
43 Wen, Y.F., K.A. Culhane-Pera, B. Thyagarajan, J.R. Bishop, et al., Potential Clinical Relevance of Differences in Allele Frequencies Found within Very Important Pharmacogenes between Hmong and East Asian Populations. Pharmacotherapy, 2020. 40(2): p. 142-152.31884695
44 Hariprakash, J.M., S.K. Vellarikkal, P. Keechilat, A. Verma, et al., Pharmacogenetic landscape of DPYD variants in south Asian populations by integration of genome-scale data. Pharmacogenomics, 2018. 19(3): p. 227-241.29239269
45 Thomas, F., I. Hennebelle, C. Delmas, I. Lochon, et al., Genotyping of a family with a novel deleterious DPYD mutation supports the pretherapeutic screening of DPD deficiency with dihydrouracil/uracil ratio. Clin Pharmacol Ther, 2016. 99(2): p. 235-42.26265035
46 Caudle, K.E., C.F. Thorn, T.E. Klein, J.J. Swen, et al., Clinical Pharmacogenetics Implementation Consortium guidelines for dihydropyrimidine dehydrogenase genotype and fluoropyrimidine dosing. Clin Pharmacol Ther, 2013. 94(6): p. 640-5.23988873
47 Toren, W., D. Ansari, B. Andersson, L. Spelt, and R. Andersson, Thymidylate synthase: a predictive biomarker in resected colorectal liver metastases receiving 5-FU treatment. Future Oncol, 2018. 14(4): p. 343-351.29318904
48 Pellicer, M., X. Garcia-Gonzalez, M.I. Garcia, L. Robles, et al., Identification of new SNPs associated with severe toxicity to capecitabine. Pharmacol Res, 2017. 120: p. 133-137.28347776
49 Abbasian, M.H., N. Ansarinejad, B. Abbasi, M. Iravani, et al., The Role of Dihydropyrimidine Dehydrogenase and Thymidylate Synthase Polymorphisms in Fluoropyrimidine-Based Cancer Chemotherapy in an Iranian Population. Avicenna J Med Biotechnol, 2020. 12(3): p. 157-164.32695278
50 Chao, Y.L. and C.K. Anders, TYMS Gene Polymorphisms in Breast Cancer Patients Receiving 5-Fluorouracil-Based Chemotherapy. Clin Breast Cancer, 2018. 18(3): p. e301-e304.28899623
51 Castro-Rojas, C.A., A.R. Esparza-Mota, F. Hernandez-Cabrera, V.J. Romero-Diaz, et al., Thymidylate synthase gene variants as predictors of clinical response and toxicity to fluoropyrimidine-based chemotherapy for colorectal cancer. Drug Metab Pers Ther, 2017. 32(4): p. 209-218.29257755
52 Hamzic, S., D. Kummer, T.K. Froehlich, M. Joerger, et al., Evaluating the role of ENOSF1 and TYMS variants as predictors in fluoropyrimidine-related toxicities: An IPD meta-analysis. Pharmacol Res, 2020. 152: p. 104594.31838077
53 Wilks, A.B. and M.W. Saif, First Case of Foot Drop Associated with Capecitabine in a Patient with Thymidylate Synthase Polymorphism. Cureus, 2017. 9(1): p. e995.28280649
54 Marsh, S., D.J. Van Booven, and H.L. McLeod. Very Important Pharmacogene: TYMS. 2019 10 October 2019 September 2020]; Available from: https://www.pharmgkb.org/vip/PA166165418.
55 Saif, M.W., Capecitabine-induced cerebellar toxicity and TYMS pharmacogenetics. Anticancer Drugs, 2019. 30(4): p. 431-434.30875351
56 Mandola, M.V., J. Stoehlmacher, S. Muller-Weeks, G. Cesarone, et al., A novel single nucleotide polymorphism within the 5' tandem repeat polymorphism of the thymidylate synthase gene abolishes USF-1 binding and alters transcriptional activity. Cancer Res, 2003. 63(11): p. 2898-904.12782596
57 CPIC. Genes-Drugs. 2020 17 Sept 2020 18 Sept 2020]; Available from: https://cpicpgx.org/genes-drugs/.
58 Kasi, P.M., T. Koep, E. Schnettler, F. Shahjehan, et al., Feasibility of Integrating Panel-Based Pharmacogenomics Testing for Chemotherapy and Supportive Care in Patients With Colorectal Cancer. Technol Cancer Res Treat, 2019. 18: p. 1533033819873924.31533552
59 De Falco, V., M.I. Natalicchio, S. Napolitano, N. Coppola, et al., A case report of a severe fluoropyrimidine-related toxicity due to an uncommon DPYD variant. Medicine (Baltimore), 2019. 98(21): p. e15759.31124962
60 Henricks, L.M., L.N. van Merendonk, D. Meulendijks, M.J. Deenen, et al., Effectiveness and safety of reduced-dose fluoropyrimidine therapy in patients carrying the DPYD*2A variant: A matched pair analysis. Int J Cancer, 2019. 144(9): p. 2347-2354.30485432
61 Martens, F.K., D.W. Huntjens, T. Rigter, M. Bartels, et al., DPD Testing Before Treatment With Fluoropyrimidines in the Amsterdam UMCs: An Evaluation of Current Pharmacogenetic Practice. Front Pharmacol, 2019. 10: p. 1609.32047438
62 Stavraka, C., A. Pouptsis, L. Okonta, K. DeSouza, et al., Clinical implementation of pre-treatment DPYD genotyping in capecitabine-treated metastatic breast cancer patients. Breast Cancer Res Treat, 2019. 175(2): p. 511-517.30746637
63 Kleinjan, J.P., I. Brinkman, R. Bakema, J.J. van Zanden, and J.M. van Rooijen, Tolerance-based capecitabine dose escalation after DPYD genotype-guided dosing in heterozygote DPYD variant carriers: a single-center observational study. Anticancer Drugs, 2019. 30(4): p. 410-415.30628914
64 Henricks, L.M., C. Lunenburg, F.M. de Man, D. Meulendijks, et al., DPYD genotype-guided dose individualisation of fluoropyrimidine therapy in patients with cancer: a prospective safety analysis. Lancet Oncol, 2018. 19(11): p. 1459-1467.30348537
65 van Staveren, M.C., H.J. Guchelaar, A.B. van Kuilenburg, H. Gelderblom, and J.G. Maring, Evaluation of predictive tests for screening for dihydropyrimidine dehydrogenase deficiency. Pharmacogenomics J, 2013. 13(5): p. 389-95.23856855
66 Meulendijks, D., A. Cats, J.H. Beijnen, and J.H. Schellens, Improving safety of fluoropyrimidine chemotherapy by individualizing treatment based on dihydropyrimidine dehydrogenase activity - Ready for clinical practice? Cancer Treat Rev, 2016. 50: p. 23-34.27589829

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance to nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

## Related Summaries by Gene

Fluorouracil Therapy and DPYD Genotype

## Tests in GTR by Condition

Capecitabine response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN077963&term=CN077963[DISCUI]&display_string=Capecitabine response)

## Tests in GTR by Gene

DPYD gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1806[geneid]+AND+CN077963[cui])

TYMS gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=7298[geneid]+AND+CN077963[cui])