# Brivaracetam Therapy and CYP2C19 Genotype

## Introduction

Brivaracetam (brand name Briviact) is an antiseizure medication used in the treatment of focal epilepsy in adults and children. It is thought to act by binding to a synaptic vesicle glycoprotein, SV2A, and reducing the release of neurotransmitters.

Brivaracetam is primarily metabolized by hydrolysis, via amidase enzymes, to an inactive metabolite. To a lesser extent, it is also metabolized via CYP2C19-dependent hydroxylation.

Individuals who have no CYP2C19 enzyme activity, “CYP2C19 poor metabolizers”, will have a greater exposure to standard doses of brivaracetam. Because they are less able to metabolize the drug to its inactive form for excretion, they may have an increased risk of adverse effects. The most common adverse effects of brivaracetam therapy include sedation, fatigue, dizziness, and nausea.

The recommended starting dosage for brivaracetam monotherapy or adjunctive therapy is 50 mg twice daily (100 mg per day). Based on how the individual responds, the dose of brivaracetam may be decreased to 25 mg twice daily (50 mg per day) or increased up to 100 mg twice daily (200 mg per day) (1).

The FDA-approved drug label for brivaracetam states that individuals who are CYPC19 poor metabolizers, or are taking medicines that inhibit CYP2C19, may require a dose reduction (Table 1) (1). The FDA-approved label further recommends an increase brivaracetam dose up to double the normal dose when used with rifampin due to induction of CYP2C19 activity and reduced brivaracetam plasma levels (1).

Table 1.

Recommendations for Brivaracetam and CYP2C19, FDA 2025

Phenotype | Recommendations
CYP2C19 poor metabolizer | May require dose reduction of brivaracetam.
Individuals using inhibitors of CYP2C19 | May require dose reduction of brivaracetam.
CYP2C19 induction due to rifampin | Increase brivaracetam dose by up to 100% (double the dosage) in individuals with concomitant rifampin treatment.

This table is adapted from (1).

## Drug: Brivaracetam

Brivaracetam is an antiseizure medication (ASM) that is used in the treatment of focal seizures in individuals aged 1 month or older in the United States (US), 2 years of age or older in the European Union, and 4 years of age or older in Canada (1, 2, 3). In the US, brivaracetam can be used as monotherapy or in combination with other ASMs (1). Approval in Europe and Canada are limited to adjuvant use of brivaracetam (2, 3). There is also evidence to suggest that brivaracetam may be useful in the treatment of generalized seizures, post-stroke epilepsy, epileptic encephalopathy, and other types of seizures (4, 5, 6, 7). A 2026 review of published clinical studies and clinical practice guidelines strongly recommends adjunctive brivaracetam in adult individuals with focal seizures, with a cautious recommendation for its use in other scenarios such as adjuvant therapy in adult generalized seizures and pediatric focal seizures (8).

Brivaracetam displays a high and selective affinity for SV2A in the brain, which is thought to contribute to the antiseizure effect (9). In a neuron, at the synapse, vesicles store various neurotransmitters. The neurotransmitters are released and then refilled in a process regulated by voltage-dependent calcium channels. These synaptic vesicles are essential for propagating nerve impulses between neurons, and the SV2A protein is a major component of the vesicle (10). Brivaracetam binding to the SV2A protein is hypothesized to reduce the release of excitatory neurotransmitters from synaptic vesicles in the brain (5).

Levetiracetam was the first ASM that was found to bind to SV2A, among other targets. Brivaracetam is an analogue of levetiracetam and was designed to selectively target SV2A with a much higher affinity, estimated to be between 10–20-fold higher (11, 12, 13).

Over 50 million people worldwide suffer from epilepsy. Epilepsy is characterized by spontaneous recurrent epileptic seizures, which may be classified as focal or generalized. Generalized seizures appear to have a specific origin but rapidly engage bilaterally distributed networks which can include cortical and subcortical structure. Generalized seizures can be further characterized as either absence seizures (sudden impaired consciousness and staring) or general tonic-clonic seizures (loss of consciousness, stiffening of limbs in the tonic phase, and twitching or jerking muscles in the clonic phase). In contrast, symptoms of focal seizures (originating within networks limited to one hemisphere) depend upon where the focus of the seizure originates; for example, jerking of a limb indicates a focus in the contralateral motor cortex. (14)

Most ASMs available target sodium channels (such as carbamazepine or phenytoin), calcium channels (for example, ethosuximide), or the GABA pathway (for example, clobazam). However, up to one-third of individuals may not achieve seizure control or they may not be able to tolerate the side effects. Newer ASMs, sometimes called third-generation medications, have unconventional targets, such as SV2A (15, 16, 17).

Brivaracetam was licensed in 2016, and in phase III trials and with long term follow up, brivaracetam was reported to be well tolerated with good efficacy (18, 19). Compared with the addition of placebo, the addition of brivaracetam to a treatment regime reduced the frequency of focal seizures by approximately half (20, 21, 22). Additional subgroup analysis of phase III trials of pediatric individuals with generalized seizures saw similar reductions in seizure frequency when brivaracetam was used as an adjuvant therapy (6).

The most common side effects associated with brivaracetam therapy include dizziness, fatigue, somnolence, nausea, and vomiting. Psychiatric symptoms such as irritability, insomnia and depression, and behavioral effects have also been reported, but some studies suggest these may be less likely to occur with brivaracetam compared with levetiracetam (23, 24, 25). Serious adverse effects have been reported that may require discontinuation of brivaracetam. These events include the potentially fatal skin and subcutaneous tissue reactions Stevens-Johnson syndrome and toxic epidermal necrolysis. Brivaracetam can also trigger bronchospasm and angioedema hypersensitivity reactions. Pediatric individuals treated with brivaracetam may also have a higher incidence of suicidal ideation than adults, this should be closely monitored. (1, 2, 3)

Analyses of the US FDA Adverse Events Reporting System (FAERS) have indicated that brivaracetam related adverse events most commonly are classified as nervous system disorders, psychiatric disorders, or injury/poisoning/procedural complications (8, 26). Aggression, insomnia, and suicidal ideation were the most common psychiatric adverse events from one such pediatric analysis (8). Another FAERS analysis reported that multiple individuals on brivaracetam reported a change in their seizure presentation or seizure-associated symptoms (26).

There is insufficient evidence to identify any risk of major birth defects, miscarriage, or other adverse maternal or fetal outcomes associated with brivaracetam use during pregnancy (1). Individuals taking brivaracetam during pregnancy are encouraged to participate in a pregnancy exposure registry such as the North American Antiepileptic Drug Pregnancy Registry in the US (1). One study from Dublin, Ireland reported on the outcomes of 34 pregnancies with known use of newer anti-seizure medications. Of the 34 individuals in the study, 8 used brivaracetam during pregnancy; 2 of those cases resulted in a spontaneous miscarriage (similar to general population rates of miscarriage) and 2 individuals (25%) developed gestational diabetes (slightly higher frequency than other medications in the study) (27).

Brivaracetam is excreted in breastmilk, with limited data showing that exclusively breastfed infants can achieve serum levels of the medication within the therapeutic range, though partial breastfeeding resulted in undetectable levels (28). Maternal use of brivaracetam is not an explicit indication to discontinue breastfeeding; experts recommend caution and monitoring for drowsiness, agitation, weight gain, and achieving developmental milestones in exclusively breastfed infants (28). The FDA-approved label advises considering the health benefits of breastfeeding along with the nursing mother’s clinical need for brivaracetam for seizure control and the risk of potential adverse effects on the breastfed infant (1).

Brivaracetam is primarily metabolized (approximately 60%) by cytochrome P450 (CYP)-independent hydrolysis (via amidase) to inactive metabolites. A minor metabolic pathway is hydroxylation by CYP2C19. The FDA, European Medicines Agency, and Health Canada -approved drug labels recommend that individuals with reduced or absent CYP2C19 activity (either due to genetic variation or drug interactions) may require a dose reduction (1, 2, 3). Drug labeling from multiple countries further states that induction of CYP2C19 activity due to rifampin coadministration may require a dose increase, with the FDA recommending up to a 100% increase in dosage (1, 2, 3). Brivaracetam administration has been shown to increase carbamazepine epoxide metabolite levels up to 2-fold via inhibition of the epoxide hydrolase (29), a drug-interaction that should be noted if brivaracetam is used in conjunction with carbamazepine.

## Gene: CYP2C19

The CYP superfamily is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs. The CYP genes are very polymorphic and can result in reduced, absent, or increased drug metabolism.

The CYP2C19 enzyme contributes to the metabolism of a range of clinically important drugs, such as antidepressants (30), benzodiazepines, several proton pump inhibitors, the antifungal agent voriconazole (31), the antiplatelet agent clopidogrel (32), and ASMs such as brivaracetam, clobazam, diazepam, lacosamide, phenytoin, and phenobarbital.

The CYP2C19 gene is highly polymorphic with over 35 variant star (*) alleles cataloged by the Pharmacogene Variation (PharmVar (https://www.pharmvar.org/)) Consortium. The CYP2C19*1 is the wild type allele and is associated with normal enzyme activity and the “normal metabolizer” phenotype. Notably, the CYP2C19*1 haplotype has been determined to include a single nucleotide polymorphism in the coding region. However, the frequency of the variant nucleotide (G) is nearly 94% globally, and this missense variant does not alter protein function (33, 34, 35). The CYP2C19*38 allele is defined by the reference sequence with no variants and is also classified as normal function (35, 36).

The CYP2C19*17 allele is associated with increased enzyme activity and, depending on the number of alleles present, is associated with the “rapid” (one CYP2C19*17 allele) and “ultrarapid” (2 CYP2C19*17 alleles) metabolizer phenotype. Non-functional alleles include CYP2C19*2 and CYP2C19*3. The CYP2C19 intermediate metabolizers “IMs" have one copy of an allele that encodes a non-functional enzyme (for example, *1/*2), whereas poor metabolizers “PMs” have 2 non-functional alleles (for example, *2/*2, *2/*3) (Table 2).

Table 2.

ClinPGx CYP2C19 Functional Status and Phenotypes

Phenotype | Genotype | Examples of diplotypes
CYP2C19 ultrarapid metabolizer (~2–5% of individuals)^a^ | An individual with 2 increased function alleles. | *17/*17
CYP2C19 rapid metabolizer (~2–30% of individuals) | An individual with one normal function allele and one increased function allele. | *1/*17
CYP2C19 normal metabolizer (~35–50% of individuals) | An individual with 2 normal function alleles. | *1/*1
CYP2C19 intermediate metabolizer (~18–45% of individuals) | An individual with one normal function allele and one no function allele, or one no function allele and one increased function allele. | *1/*2 *1/*3 *2/*17
CYP2C19 poor metabolizer (~2–15% of individuals) | An individual with 2 no function alleles. | *2/*2 *2/*3 *3/*3

^a^ CYP2C19 metabolizer status frequencies are based on average multiethnic frequencies.

See the CYP2C19 Frequency Tables for population-specific allele and phenotype frequencies; see Allele Functionality Reference table for additional allele classifications and Diplotype-Phenotype table (37).

Approximately 2% of Caucasians, 4% of African Americans, 14% of Chinese, and 57% of Oceanians are CYP2C19 PM, while up to 45% of individuals are CYP2C19 IM (38).

The most common no-function allele is CYP2C19*2, which contains the NM_000769.1:c.681G>A variant in exon 5. This results in an aberrant splice site and produces a truncated, non-functioning protein. The CYP2C19*2 allele frequencies are between 12–18% in individuals of European, American, or African ancestry; 25–35% in Asians, Native Hawaiians, and Pacific Islanders; and up to 60% in Oceanian populations (38, 39).

For CYP2C19, another commonly tested no-function variant is CYP2C19*3, which contains a c.636G>A variant in exon 4 that causes a premature stop codon. The CYP2C19*3 allele frequencies are ~2–9% in Asian populations but are rare in other ancestral populations (39). Other non-functional variants, such as CYP2C19*4–*8, occur in less than 1% of the general population (32).

The frequency of the increased function CYP2C19*17 allele is approximately 22% in individuals of European ancestry, 8% in individuals from the Americas, 0.5–5.7% in Asian, Native Hawaiian, and Pacific Islander populations, 17% in African populations, and 20% in African American and Afro-Caribbean populations (38, 39).

Phenoconversion due to CYP2C19 Inhibitors and Inducers

Other medications can impact the expression or activity level of CYP2C19. Rifampin is a potent inducer of CYP2C19 and when used together with brivaracetam, it may be necessary to increase the dose of brivaracetam (as much as double) to achieve the desired therapeutic levels (1). This recommendation is based on findings that co-administration of rifampin (a strong enzyme inducer) decreased exposure to brivaracetam by 45% (40).

There is some evidence that other medications may also alter exposure to brivaracetam, including the medications lopinavir/ritonavir, chloroquine, hydroxychloroquine, and ribavirin, though the mechanism of this interaction is unclear (41). Another ASM, cenobamate, also can increase plasma levels of brivaracetam, most likely due to CYP2C19 inhibition (42). Adjuvant cannabidiol therapy has been reported to increase brivaracetam levels in a small number of individuals, possibly due to CYP2C19 inhibition, an unknown mechanism, or a combination of multiple factors (43). It should be noted that at the time of writing no actionable guidelines (other than rifampin) are available regarding drug-drug or drug-drug-gene interactions for brivaracetam and CYP2C19.

## Linking Gene Variation with Treatment Response

One small study (n=79) reports that CYP2C19 allele status influences the pharmacokinetics of brivaracetam, but that this is unlikely to be clinically relevant because of the minor role of CYP-dependent hydroxylation in the metabolism of brivaracetam (44). However, the FDA does state that CYP2C19 poor metabolizers may require a reduction in the dose of brivaracetam (1).

It is possible that genetic variations associated with a loss of CYP2C19 function may reduce brivaracetam metabolism leading to increased levels of active drug levels in the plasma and possibly increase the probability of side effects. However, the recommended therapeutic dose is 50–200 mg/day, and individuals are managed via dose titration to optimal efficacy, safety, and tolerability. The limited clinical impact of CYP2C19 genotype and drug-drug interactions is supported by a physiologically based pharmacokinetic model of brivaracetam pharmacokinetics (45).

## Genetic Testing

Clinical genotyping tests are available for several CYP2C19 alleles. The NIH’s Genetic Testing Registry (GTR) provides examples of the genetic tests that are available for the CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1557%5Bgeneid%5D) or brivaracetam response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN781941&filter=testtype:clinical).

Usually, an individual’s result is reported as a diplotype, such as CYP2C19 *1/*1, and may also include an interpretation of the individual’s predicted metabolizer phenotype (ultrarapid, rapid, normal, intermediate, or poor). Tools are available from ClinPGx to facilitate genotype to phenotype conversion and identify available pharmacogenetic guidance based on genotype (see https://www.clinpgx.org/ for additional information) (46, 47).

The CYP2C19*2 and CYP2C19*3 alleles are commonly tested for, and Table 2 summarizes CYP2C19 genotype-based phenotypes. Less common non-functional alleles (for example, CYP2C19*4-*8) may also influence drug response similarly to CYP2C19*2 and CYP2C19*3 but they may not be tested for, and data are lacking on their effects on the brivaracetam drug response.

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in real-world clinical settings (48, 49, 50). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, where gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (51). Real-world implementation of pharmacogenetic testing for epilepsy management has been reported with successful utilization of a saliva-based test (52), though providers should review available professional guidelines when utilizing pharmacogenetic testing to guide prescribing.

To facilitate CYP2C19 genetic testing and improve genotyping concordance across laboratories, the Pharmacogenetics Working Group of the Association for Molecular Pathology (AMP) Clinical Practice Committee has recommended a minimum set of CYP2C19 alleles referred to as “Tier 1” which should be included in clinical CYP2C19 pharmacogenomic tests. As of 2018, the “Tier 1” alleles are CYP2C19*2, *3, and *17 (Table 3) (53).

In addition, “Tier 2” alleles are optional, and AMP recommends that testing laboratories consider *4, *5, *6, *7, *8, *9, *10, and *35 (Table 4). These alleles have all been shown to have decreased or no function but have either a low minor allele frequency, limited data characterizing the impact on enzyme function, or lack reference materials. Among the ‘Tier 2’ alleles, the CYP2C19*35 allele is the most common, with a frequency of 9% in African populations (53).

Table 3.

AMP (2018) CYP2C19 Tier 1 Variant Alleles.

Allele | Allele functional status (CPIC)^a^
CYP2C19*2 | No function
CYP2C19*3 | No function
CYP2C19*17 | Increased function

^a^ Citations for assignment of function, as provided by the Clinical Pharmacogenetics Implementation Consortium (CPIC), can be found on the ClinPGx Gene-specific Information for CYP2C19 (https://www.clinpgx.org/page/cyp2c19RefMaterials).

Both Table 3 and Table 4 are adapted from (53).

Table 4.

AMP (2018) CYP2C19 Tier 2 Variant Alleles.

Genotype | Allele functional status (CPIC) ^a^
CYP2C19*4 | No function
CYP2C19*5 | No function
CYP2C19*6 | No function
CYP2C19*7 | No function
CYP2C19*8 | No function
CYP2C19*9 | Decreased function
CYP2C19*10 | Decreased function
CYP2C19*35 | No function

^a^ Citations for assignment of function, as provided by the Clinical Pharmacogenetics Implementation Consortium (CPIC), can be found at ClinPGx Gene-specific Information for CYP2C19 (https://www.clinpgx.org/page/cyp2c19RefMaterials)

Both Table 3 and Table 4 are adapted from (53).

## The CYP2C19 Gene Interactions with Medications Used for Additional Indications

The CYP2C19 protein is involved in the metabolism of many other medications, including ASMs that may be used with brivaracetam. Other medications affected by CYP2C19 genetic variation may be used to treat:

- Acute coronary syndrome –– individuals who are CYP2C19 poor metabolizers and undergoing percutaneous coronary intervention have an increased risk of cardiovascular events if they are treated with the antiplatelet drug clopidogrel (a pro-drug that is activated by CYP2C19-mediated metabolism).
- Gastrointestinal ulcers, gastroesophageal reflux, erosive esophagitis, and Helicobacter pylori infection—PPIs like omeprazole (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/omeprazole/), esomeprazole (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/esomeprazole/), and others may have reduced metabolism in CYP2C19 IMs and PMs and thus these individuals have higher exposure to these medications, which imparts risk of adverse events. Conversely, CYP2C19*17 confers increased activity and thus a more rapid clearance of PPIs and potential for treatment failure in ultrarapid metabolizers (UMs).
- Fungal infection—voriconazole (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/voriconazole/) is metabolized by CYP2C19 and UMs may have delayed target blood concentrations due to rapid clearance; PMs may experience high exposure and have a risk of adverse events.
- Depression, anxiety disorders, obsessive-compulsive disorder, or migraine prophylaxis—both selective serotonin reuptake inhibitors (SSRIs, such as citalopram, escitalopram, and sertraline) and tricyclic antidepressants (TCAs, such as the tertiary amines amitriptyline (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/amitriptyline/), clomipramine, doxepin, imipramine (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/imipramine/), and trimipramine) can be metabolized by CYP2C19. When administering SSRIs, UMs may experience treatment failure due to high clearance while PMs may require dose reduction. For the tertiary amine TCAs, UMs may experience altered responses or side effects due to rapid conversion to secondary amines while PMs are at risk of suboptimal responses and may require a lower dose. Diazepam (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/diazepam/) is also partially metabolized by CYP2C19 and altered enzyme function may contribute to altered clearance of this medication.
- Musculoskeletal pain—carisoprodol (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/carisoprodol/), a centrally acting muscle relaxant, is metabolized by CYP2C19 and PMs may be at a higher risk of carisoprodol toxicity.
- Hypoactive sexual desire disorder—flibanserin (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/flibanserin/) is metabolized, in part, by CYP2C19; PMs have a higher exposure to this medication, resulting in an elevated risk of hypotension, syncope, and CNS depression.

Additional information on gene-drug interactions for CYP2C19 are available from ClinPGx (https://www.clinpgx.org/), CPIC (https://www.clinpgx.org/cpic/pairs) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2C19”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2025 Statement from the US Food and Drug Administration (FDA)

Brivaracetam is primarily metabolized by hydrolysis of the amide moiety to form the corresponding carboxylic acid metabolite, and secondarily by hydroxylation on the propyl side chain to form the hydroxy metabolite. The hydrolysis reaction is mediated by hepatic and extra-hepatic amidase. The hydroxylation pathway is mediated primarily by CYP2C19. In human subjects possessing genetic variations in CYP2C19, production of the hydroxy metabolite is decreased 2-fold or 10-fold, while the blood level of brivaracetam itself is increased by 22% or 42%, respectively, in individuals with one or both mutated alleles. CYP2C19 poor metabolizers and patients using inhibitors of CYP2C19 may require dose reduction. An additional hydroxy acid metabolite is created by hydrolysis of the amide moiety on the hydroxy metabolite or hydroxylation of the propyl side chain on the carboxylic acid metabolite (mainly by CYP2C9). None of the 3 metabolites are pharmacologically active.

[…]

Co-administration with rifampin decreases brivaracetam plasma concentrations likely because of CYP2C19 induction. Prescribers should increase the brivaracetam dose by up to 100% (i.e., double the dosage) in patients while receiving concomitant treatment with rifampin.

Please review the complete therapeutic recommendations that are located here: (1).

## Nomenclature for Selected CYP2C19 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2C19*2 ^[1]^ | 681G>A | NM_000769.1:c.681G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | NP_000760.1:p.Pro227= | rs4244285 (https://www.ncbi.nlm.nih.gov/snp/rs4244285)
CYP2C19*2 ^[1]^ | 12662A>G | NM_000769.1:c.332-23A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633850/) | (Splicing defect) | rs12769205 (https://www.ncbi.nlm.nih.gov/snp/rs12769205)
CYP2C19*2 ^[1]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*3 ^[1]^ | 636G>A | NM_000769.1:c.636G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | NP_000760.1:p.Trp212Ter | rs4986893 (https://www.ncbi.nlm.nih.gov/snp/4986893)
CYP2C19*3 ^[1]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*4 ^[2]^ | 1A>G | NM_000769.4:c.1A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/16900/) | NP_000760.1:p.Met1Val | rs28399504 (https://www.ncbi.nlm.nih.gov/snp/rs28399504)
CYP2C19*4 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*5 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*5 ^[2]^ | 90033C>T | NM_000769.4:c.1297C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16898) | NP_000760.1:p.Arg433Trp | rs56337013 (https://www.ncbi.nlm.nih.gov/snp/rs56337013)
CYP2C19*6 ^[2]^ | 12748G>A | NM_000769.4:c.395G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39350) | NP_000760.1:p.Arg132Gln | rs72552267 (https://www.ncbi.nlm.nih.gov/snp/rs72552267)
CYP2C19*6 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*7 ^[2]^ | 19294T>A | NM_000769.4:c.819+2T>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39348/) | (Splicing defect) | rs72558186 (https://www.ncbi.nlm.nih.gov/snp/rs72558186)
CYP2C19*7 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*8 ^[2]^ | 12711T>C | NM_000769.4:c.358T>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39351/) | NP_000760.1:p.Trp120Arg | rs41291556 (https://www.ncbi.nlm.nih.gov/snp/rs41291556)
CYP2C19*8 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*9 ^[2]^ | 12784G>A | NM_000769.1:c.431G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39352/) | NP_000760.1:p.Arg144His | rs17884712 (https://www.ncbi.nlm.nih.gov/snp/rs17884712)
CYP2C19*9 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*10 ^[2]^ | 19153C>T | NM_000769.4:c.680C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39353/) | NP_000760.1:p.Pro227Leu | rs6413438 (https://www.ncbi.nlm.nih.gov/snp/rs6413438)
CYP2C19*10 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*16 | 90060C>T | NM_000769.4:c.1324C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/633849/) | NP_000760.1:p.Arg442Cys | rs192154563 (https://www.ncbi.nlm.nih.gov/snp/rs192154563)
CYP2C19*17 ^[1] [3]^ | -806C>T | NG_008384.3:g.4220C>T (NM_000769.2:c.-806C>T)^[3]^ | Not applicable—variant occurs in a non-coding region | rs12248560 (https://www.ncbi.nlm.nih.gov/snp/12248560)
CYP2C19*19 | 151A>G | NM_000769.4:c.151A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633933/) | NP_000760.1:p.Ser51Gly | rs1564657013 (https://www.ncbi.nlm.nih.gov/snp/rs1564657013)
CYP2C19*19 | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*35 ^[2]^ | 12662A>G | NM_000769.1:c.332-23A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633850/) | (Splicing defect) | rs12769205 (https://www.ncbi.nlm.nih.gov/snp/rs12769205)
CYP2C19*35 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)

^[1]^ AMP Tier 1 allele (53)

^[2]^ AMP Tier 2 allele (53)

^[3]^ The CYP2C19*17 allele has increased expression due to an upstream, non-coding variant. The legacy HGVS expression for the change relative to the coding sequence is provided, but the correct RefSeq genomic sequence is provided as well.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (54).

Nomenclature for Cytochrome P450 enzymes is available from the PharmVar database (55) https://www.pharmvar.org/

## Acknowledgments

Version 1.0 (Published May 15, 2018): The author would like to thank Ben Kong, PharmD, BCPS, Clinical Pharmacist, Oregon Health & Science University, Portland, OR, USA; Gouri Mukerjee, Scientific Officer at Geneyouin Inc., Toronto, Canada; Michael A. Rogawski, Professor of Neurology, University of California, Davis, Davis, CA, USA; and Armel Stockis, UCB Pharma, Brussels, Belgium; for reviewing this summary.

Version 2.0 (Published March 3, 2026): The authors would like to thank Ben Kong, Pharm. D., Clinical Pharmacist, Oregon Health & Science University, Knight Cancer Institute, Portland, Oregon, USA and Won-Joo Kim, MD, PhD, Department of Neurology, Gangnam Severance Hospital, Yonsei University, College of Medicine, Seoul, Korea, for reviewing this summary

## Version History

Version 1.0 of this chapter was published on May 15, 2018 and can be accessed here.

Version 2.0 of this chapter was published on March 3, 2026. This update includes expanded guidance from FDA regarding the age range and indications for use of the medication, regulatory information from European and Canadian health agencies regarding brivaracetam use, and updated allele definitions from CPIC. There is no change regarding recommendations for authoritative genotype-guided dosing recommendations cited in the document compared to the previous chapter version.

A minor revision (v 2.1) was made on May 18, 2026, to address a formatting error in the chapter title and update links related to CPIC and ClinPGx resources.

## References

1 BRIVIACT- brivaracetam tablet, film coated; BRIVIACT- brivaracetam solution; BRIVIACT- brivaracetam injection, suspension [Packet insert]. Smyrna, GA: UCB, I.; 2025. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=3cf2f439-0e97-443e-8e33-25ecef616f6c.
2 Briviact : EPAR - Product Information. Brussels, Belgium: UCB Pharma SA; 2025. Available from: https://www.ema.europa.eu/en/medicines/human/EPAR/briviact-italy-nubriveo.
3 ZDS-BRIVARACETAM Product Monograph. Gujarat, India: Zydus Lifesciences Limited; 2025. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=106666.
4 Grande-Martín, A., D. Sopelana-Garay, J.M. Pardal-Fernandez, R.M. Sanchez-Honrubia, et al., Exceptional response to brivaracetam in a patient with refractory idiopathic generalized epilepsy and absence seizures. Epileptic Disord, 2018. 20(1): p. 60–64.29160210
5 Hwang, H. and W.J. Kim, Brivaracetam: Pharmacology, Clinical Efficacy, and Safety in Epilepsy. J Epilepsy Res, 2025. 15(1): p. 42–55.40568060
6 Bourikas, D., S. Elmoufti, J.P. Elshoff, A. Little, et al., Long-term tolerability and efficacy of adjunctive brivaracetam in pediatric patients with generalized-onset seizures: Subgroup analysis of an open-label, follow-up trial. Epilepsy Behav, 2025. 171: p. 110569.40737960
7 Russo, A., V. Cuteri, L. Bansal, P. Bonanni, et al., Brivaracetam in treating epileptic encephalopathy and refractory focal epilepsies in patients under 14 years of age. Iran J Child Neurol, 2021. 15(4): p. 95–104.34782846
8 Wu, X., Y. Chen, L. Feng, X. Han, et al., Clinical practice guidelines for the administration of third-generation anti-seizure medications. Seizure, 2026. 134: p. 13–26.41270420
9 Niespodziany, I., J.M. Rigo, G. Moonen, A. Matagne, et al., Brivaracetam does not modulate ionotropic channels activated by glutamate, gamma-aminobutyric acid, and glycine in hippocampal neurons. Epilepsia, 2017. 58(11): p. e157–e161.28850675
10 Khaleghi, F. and E.C. Nemec, 2nd, Brivaracetam (Briviact): A Novel Adjunctive Therapy for Partial-Onset Seizures. P T, 2017. 42(2): p. 92–96.28163554
11 Kwok, C.S., E.L. Johnson, and G.L. Krauss, Comparing Safety and Efficacy of "Third-Generation" Antiepileptic Drugs: Long-Term Extension and Post-marketing Treatment. CNS Drugs, 2017. 31(11): p. 959–974.29204953
12 Rogawski, M.A., A New SV2A Ligand for Epilepsy. Cell, 2016. 167(3): p. 587.27768878
13 Wood, M.D. and M. Gillard, Evidence for a differential interaction of brivaracetam and levetiracetam with the synaptic vesicle 2A protein. Epilepsia, 2017. 58(2): p. 255–262.28012162
14 Beniczky, S., E. Trinka, E. Wirrell, F. Abdulla, et al., Updated classification of epileptic seizures: Position paper of the International League Against Epilepsy. Epilepsia, 2025. 66(6): p. 1804–1823.40264351
15 Ben-Menachem, E., R. Mameniskiene, P.P. Quarato, P. Klein, et al., Efficacy and safety of brivaracetam for partial-onset seizures in 3 pooled clinical studies. Neurology, 2016. 87(3): p. 314–23.27335114
16 Milovanović, J.R., S.M. Jankovic, A. Pejcic, M. Milosavljevic, et al., Evaluation of brivaracetam: a new drug to treat epilepsy. Expert Opin Pharmacother, 2017. 18(13): p. 1381–1389.28737479
17 Russo, E., R. Citraro, and M. Mula, The preclinical discovery and development of brivaracetam for the treatment of focal epilepsy. Expert Opin Drug Discov, 2017. 12(11): p. 1169–1178.28829199
18 Toledo, M., J. Whitesides, J. Schiemann, M.E. Johnson, et al., Safety, tolerability, and seizure control during long-term treatment with adjunctive brivaracetam for partial-onset seizures. Epilepsia, 2016. 57(7): p. 1139–51.27265725
19 Brigo, F., N.L. Bragazzi, R. Nardone, and E. Trinka, Efficacy and tolerability of brivaracetam compared to lacosamide, eslicarbazepine acetate, and perampanel as adjunctive treatments in uncontrolled focal epilepsy: Results of an indirect comparison meta-analysis of RCTs. Seizure, 2016. 42: p. 29–37.27710868
20 Brandt, C., T.W. May, and C.G. Bien, Brivaracetam as adjunctive therapy for the treatment of partial-onset seizures in patients with epilepsy: the current evidence base. Ther Adv Neurol Disord, 2016. 9(6): p. 474–482.27800023
21 Li-Na, Z., C. Deng, W. Hai-Jiao, X. Da, et al., Indirect comparison of third-generation antiepileptic drugs as adjunctive treatment for uncontrolled focal epilepsy. Epilepsy Res, 2018. 139: p. 60–72.29197667
22 Hoy, S.M., Brivaracetam: A Review in Partial-Onset (Focal) Seizures in Patients with Epilepsy. CNS Drugs, 2016. 30(8): p. 761–72.27503181
23 Brodie, M.J., Tolerability and Safety of Commonly Used Antiepileptic Drugs in Adolescents and Adults: A Clinician's Overview. CNS Drugs, 2017. 31(2): p. 135–147.28101765
24 Ortega, G., L. Abraira, G. Marti, M. Quintana, et al., Anger Assessment in Patients Treated With Brivaracetam. Clin Neuropharmacol, 2018. 41(1): p. 6–9.29194113
25 Zaccara, G., F. Giovannelli, F.S. Giorgi, V. Franco, et al., Tolerability of new antiepileptic drugs: a network meta-analysis. Eur J Clin Pharmacol, 2017. 73(7): p. 811–817.28378057
26 Meng, Z., X. Li, Y. Liao, F. Feng, et al., Real-world safety evaluation of brivaracetam: insights from the US FDA Adverse Event Reporting System. Expert Opin Drug Saf, 2025: p. 1–8.39873480
27 Devin, J.E., F. O'Shaughnessy, M. Sardana, B.J. Cleary, et al., The use of newer anti-seizure medicines in women with epilepsy in pregnancy: A case series. Epilepsy Behav Rep, 2025. 29: p. 100741.39927179
28 Bivaracetam, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/29999938.
29 Moseley, B.D., C. Otoul, L. Staelens, and A. Stockis, Pharmacokinetic interaction of brivaracetam on other antiepileptic drugs in adults with focal seizures: Pooled analysis of data from randomized clinical trials. Epilepsy Res, 2019. 158: p. 106218.31675621
30 Hicks, J.K., K. Sangkuhl, J.J. Swen, V.L. Ellingrod, et al., Clinical pharmacogenetics implementation consortium guideline (CPIC) for CYP2D6 and CYP2C19 genotypes and dosing of tricyclic antidepressants: 2016 update. Clin Pharmacol Ther, 2016.27997040
31 Moriyama, B., A.O. Obeng, J. Barbarino, S.R. Penzak, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guidelines for CYP2C19 and Voriconazole Therapy. Clin Pharmacol Ther, 2016.27981572
32 Scott, S.A., K. Sangkuhl, C.M. Stein, J.S. Hulot, et al., Clinical Pharmacogenetics Implementation Consortium guidelines for CYP2C19 genotype and clopidogrel therapy: 2013 update. Clin Pharmacol Ther, 2013. 94(3): p. 317–23.23698643
33 dbSNP. rs3758581 RefSNP Report. 14 Oct 2022]; Available from: https://www.ncbi.nlm.nih.gov/snp/rs3758581.
34 ClinVar. [VCV000039354.3]. 14 Oct 2022]; Available from: https://www.ncbi.nlm.nih.gov/clinvar/variation/VCV000039354.3.
35 PharmVar. CYP2C19. 14 Oct 2022]; Available from: https://www.pharmvar.org/gene/CYP2C19.
36 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, et al., Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542–545.34091888
37 Gene-specific Information Tables for CYP2C19 [Cited 5 Feb 2026]. Available from https://www.clinpgx.org/page/cyp2c19RefMaterials.
38 CYP2C19 frequency table [Cited 29 Sept 2022]. Available from https://files.cpicpgx.org/data/report/current/frequency/CYP2C19_frequency_table.xlsx.
39 Alrajeh, K.Y. and Y.M. Roman, The frequency of major CYP2C19 genetic polymorphisms in women of Asian, Native Hawaiian and Pacific Islander subgroups. Per Med, 2022. 19(4): p. 327–339.35748236
40 Stockis, A., S. Watanabe, A.J. Scheen, D. Tytgat, et al., Effect of Rifampin on the Disposition of Brivaracetam in Human Subjects: Further Insights into Brivaracetam Hydrolysis. Drug Metab Dispos, 2016. 44(6): p. 792–9.27002062
41 Karazniewicz-Lada, M., A.K. Glowka, A.A. Mikulska, and F.K. Glowka, Pharmacokinetic Drug-Drug Interactions among Antiepileptic Drugs, Including CBD, Drugs Used to Treat COVID-19 and Nutrients. Int J Mol Sci, 2021. 22(17).34502487
42 Bender, L., M. Hirsch, and A. Schulze-Bonhage, Increase of Brivaracetam serum concentration with introduction of Cenobamate. Front Pharmacol, 2025. 16: p. 1571376.40235536
43 Klotz, K.A., M. Hirsch, M. Heers, A. Schulze-Bonhage, et al., Effects of cannabidiol on brivaracetam plasma levels. Epilepsia, 2019. 60(7): p. e74–e77.31211851
44 Stockis, A., S. Watanabe, E. Rouits, K. Matsuguma, et al., Brivaracetam single and multiple rising oral dose study in healthy Japanese participants: influence of CYP2C19 genotype. Drug Metab Pharmacokinet, 2014. 29(5): p. 394–9.24717838
45 Yang, H., L. Yang, X. Zhong, X. Jiang, et al., Physiologically based pharmacokinetic modeling of brivaracetam and its interactions with rifampin based on CYP2C19 phenotypes. Eur J Pharm Sci, 2022. 177: p. 106258.35840101
46 Li, B., K. Sangkuhl, K. Keat, R.M. Whaley, et al., How to Run the Pharmacogenomics Clinical Annotation Tool (PharmCAT). Clin Pharmacol Ther, 2023. 113(5): p. 1036–1047.36350094
47 Gong, L., M. Whirl-Carrillo, and T.E. Klein, PharmGKB, an Integrated Resource of Pharmacogenomic Knowledge. Curr Protoc, 2021. 1(8): p. e226.34387941
48 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, et al., Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89–99.35194175
49 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094–3118.34474980
50 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347–356.36739136
51 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116–3125.37277227
52 Riva, A., R. Roberti, G. D'Onofrio, M.S. Vari, et al., A real-life pilot study of the clinical application of pharmacogenomics testing on saliva in epilepsy. Epilepsia Open, 2023. 8(3): p. 1142–1150.36840436
53 Pratt VM, D.T.A., Hachad H, Ji Y, Kalman LV, Scott SA, Weck KE, Recommendations for Clinical CYP2C19 Genotyping Allele Selection: A Report of the Association for Molecular Pathology. J Mol Diagn, 2018. 20(3): p. 269–276.29474986
54 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564–9.26931183
55 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399–401.29134625

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Carisoprodol Therapy and CYP2C19 Genotype

Clobazam Therapy and CYP2C19 Genotype

Clopidogrel Therapy and CYP2C19 Genotype

Clozapine Therapy and CYP Genotype

Diazepam Therapy and CYP2C19 Genotype

Esomeprazole Therapy and CYP2C19 Genotype

Flibanserin Therapy and CYP2C19 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Lacosamide Therapy and CYP2C19 Genotype

Omeprazole Therapy and CYP2C19 Genotype

Prasugrel Therapy and CYP Genotype

Voriconazole Therapy and CYP2C19 Genotype

## Related Summaries by Drug Class

Lacosamide Therapy and CYP2C19 Genotype

## Tests in GTR by Gene

CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1557[geneid])