# Azathioprine Therapy and TPMT and NUDT15 Genotype

## Introduction

Azathioprine (brand names Imuran, Azasan) is an immunosuppressant that belongs to the drug class of thiopurines. It is used with other drugs to prevent kidney transplant rejection and to manage autoimmune and inflammatory conditions such as systemic lupus erythematosus, inflammatory bowel disease, systemic vasculitis, and rheumatoid arthritis.

Azathioprine is a prodrug that must first be activated to form thioguanine nucleotides (TGNs), the major active metabolites. The active metabolites are metabolized and inactivated by the enzyme thiopurine methyltransferase (TPMT) and the enzyme nudix hydrolase 15 (NUDT15). Thus, individuals with reduced activity of either enzyme are exposed to higher levels of thioguanine and have a higher risk of toxicity side effects, including severe bone marrow suppression (myelosuppression).

The FDA-approved drug label states that testing for TPMT and NUDT15 deficiency should be considered in individuals who experience severe bone marrow toxicities or repeated episodes of myelosuppression. The FDA recommends considering an alternative therapy for individuals who are known to have homozygous TPMT or NUDT15 deficiency, or both, and to reduce dosages for individuals who have a no function allele, cautioning that a more substantial dose reduction may be required for individuals who are either TPMT or NUDT15 poor metabolizers (Table 1) (1).

Dosing recommendations for thioguanine based on TPMT and NUDT15 genotype have also been published by the Clinical Pharmacogenetics Implementation Consortium (CPIC, Table 2, Table 3) and the Dutch Pharmacogenetics Working Group (DPWG). Both the CPIC and DPWG guidelines recommend specific dose reductions for individuals who have low or deficient enzyme activity, including starting dose and more information on how and when to adjust the dose e.g., the time allowed to reach steady state after each dose adjustment (2-4).

Table 1.

FDA Drug Label Dosage and Administration of Azathioprine (2020)

Enzyme | Dosage and administration
TPMT | - Individuals with thiopurine S-methyl transferase (TPMT) or nucleotide diphosphatase (NUDT15) deficiency may be at an increased risk of severe and life-threatening myelotoxicity if receiving conventional doses of azathioprine.; - Death associated with pancytopenia has been reported in individuals with absent TPMT activity receiving azathioprine.; - In individuals with severe myelosuppression, consider evaluation for TPMT and NUDT15 deficiency.; - Consider alternative therapy in individuals with homozygous* TPMT or NUDT15 deficiency and reduced dosages in individuals with heterozygous deficiency.
NUDT15

* This also applies to compound heterozygous TPMT or NUDT15 deficiency, as multiple no function alleles exist. See Tables 4 and 5.

This FDA table is adapted (1).

Table 2.

CPIC Recommended Dosing of Azathioprine by TPMT Phenotype (2018 Update)

Phenotype | Implications for azathioprine phenotypic measures | Dosing recommendations for azathioprine | Classification of recommendations^b^
TPMT normal metabolizer | Lower concentrations of TGN metabolites, higher MeTIMP, this is the “normal” pattern. Normal risk of thiopurine-related leukopenia, neutropenia, myelosuppression. | Start with the normal starting dose^a^ (e.g., 2–3 mg/kg/day) and adjust doses of azathioprine based on disease-specific guidelines. Allow 2 weeks to reach steady state after each dose adjustment. | Strong
TPMT intermediate metabolizer OR TPMT possible intermediate metabolizer | Moderate to high concentrations of TGN metabolites; low concentrations of MeTIMP. Increased risk of thiopurine-related leukopenia, neutropenia, myelosuppression. | Start with reduced starting doses (30–80% of normal dose) if normal starting dose^a^ is 2–3 mg/kg/ day (e.g., 0.6–2.4 mg/kg/day), and adjust doses of azathioprine based on degree of myelosuppression and disease-specific guidelines. Allow 2–4 weeks to reach steady state after ≥ 40–60 mg/m^2^/day (e.g., 20–48 mg/m^2^/day) and adjust doses of thioguanine based on degree of myelosuppression and disease-specific guidelines. Allow 2–4 weeks to reach steady state after each dose adjustment. | Strong
TPMT poor metabolizer | Extremely high concentrations of TGN metabolites; fatal toxicity possible without dose decrease; no MeTIMP metabolites. Greatly increased risk of thiopurine-related leukopenia, neutropenia, myelosuppression. | For nonmalignant conditions, consider alternative nonthiopurine immunosuppressant therapy. For malignancy, start with drastically reduced doses (reduce daily dose^a^ by 10-fold and dose 3 times weekly instead of daily) and adjust doses of azathioprine based on degree of myelosuppression and disease-specific guidelines. Allow 4–6 weeks to reach steady state after each dose adjustment. | Strong

MeTIMP, metabolites of thiopurine methyltransferase; TGN, thioguanine nucleotides; TPMT, thiopurine methyltransferase.^a^Normal starting doses vary by race/ethnicity and treatment regimens. If the standard dose is below the normal recommended dose, a dose reduction might not be recommended for intermediate metabolizers.

^b^ Rating scheme described in Supplemental Material (2).

This CPIC table is adapted from (2).

Note, CPIC have also published recommendations for thiopurine dosing when the status of both TPMT and NUDT15 is known. Please see (2).

Table 3.

CPIC Recommended Dosing of Azathioprine by NUDT15 Phenotype (2018 Update)

Phenotype | Implications for azathioprine phenotypic measures | Dosing recommendations for azathioprine | Classification of recommendations^b^
NUDT15 normal metabolizer | Normal risk of thiopurine-related leukopenia, neutropenia, myelosuppression | Start with the normal starting dose^a^ (e.g., 2–3 mg/kg/day) and adjust doses of azathioprine based on disease-specific guidelines. Allow 2 weeks to reach steady state after each dose adjustment. | Strong
NUDT15 intermediate metabolizer OR NUDT15 possible intermediate metabolizer | Increased risk of thiopurine-related leukopenia, neutropenia, myelosuppression | Start with reduced starting doses (30–80% of normal dose) if normal starting dose^a^ is 2–3 mg/kg/day (e.g., 0.6–2.4 mg/kg/day), and adjust doses of azathioprine based on degree of myelosuppression and disease-specific guidelines. Allow 2–4 weeks to reach steady state after each dose adjustment. | Strong
NUDT15 poor metabolizer | Greatly increased risk of thiopurine-related leukopenia, neutropenia, myelosuppression | For nonmalignant conditions, consider alternative nonthiopurine immunosuppressant therapy. For malignant conditions, start with drastically reduced normal daily doses^a^ (reduce daily dose by 10-fold) and adjust doses of azathioprine based on degree of myelosuppression and disease-specific guidelines. Allow 4–6 weeks to reach steady state after each dose adjustment. | Strong

^a^ Normal starting doses vary by race/ethnicity and treatment regimens. If the standard dose is below the normal recommended dose, dose reduction might not be recommended for intermediate metabolizers.

^b^ Rating scheme described in Supplemental Material.

This CPIC table is adapted from (2).

Note, CPIC have also published recommendations for thiopurine dosing when the status of both thiopurine methyltransferase (TPMT) and nudix hydrolase 15 (NUDT15) is known. Please see (2).

## Drug Class: Thiopurines

Thiopurines are used as anticancer agents and as immunosuppressants in inflammatory bowel disease, rheumatoid arthritis, and other autoimmune conditions. Three thiopurines are used clinically: thioguanine, mercaptopurine, and azathioprine (a prodrug for mercaptopurine).

All 3 agents have similar effects but are typically used for different indications. Thioguanine is most commonly used to treat myeloid leukemias, mercaptopurine is used for lymphoid malignancies, and mercaptopurine and azathioprine are used for immune conditions.

There is increasing evidence that DNA testing for NUDT15 and TPMT before initiating thiopurine therapy would be clinically useful. In Europeans and Africans, inherited TPMT deficiency is the primary genetic cause of thiopurine intolerance, whereas for Asians, risk alleles in NUDT15 explains most thiopurine-related myelosuppression (5, 6).

## Drug: Azathioprine

Azathioprine is an immunosuppressive agent used with other drugs to prevent rejection of kidney transplants. It is also used to manage autoimmune and other inflammatory conditions including active rheumatoid arthritis, (1) systemic lupus erythematosus, vasculitis, and inflammatory bowel disease (IBD).

Azathioprine is a slow-acting drug and for IBD, it typically takes at least 3 months of therapy before a therapeutic effect is observed. Therefore, azathioprine is used for the induction and maintenance of IBD remission rather than as a monotherapy for acute relapses. Because the discontinuation of azathioprine is associated with a high rate of relapse of IBD, azathioprine is usually continued long-term if there are no adverse effects (7-9).

The use of azathioprine or the related drug mercaptopurine has been associated with a 4-fold increased risk of developing lymphoma, which does not persist after discontinuation of therapy (10, 11).

The increased risk of malignancy led to the following boxed label on the FDA-approved drug label for azathioprine:

Malignancy: Patients receiving immunosuppressants, including azathioprine, are at increased risk of developing lymphoma and other malignancies, particularly of the skin. Physicians should inform patients of the risk of malignancy with azathioprine. As usual for patients with increased risk for skin cancer, exposure to sunlight and ultraviolet light should be limited by wearing protective clothing and using a sunscreen with a high protection factor (1).

Like all thiopurines, azathioprine is a purine analogue, and acts as an antimetabolite by interfering with nucleic acid synthesis and inhibiting purine metabolism. Azathioprine is first metabolized to mercaptopurine (6-MP), which is then bioactivated via hypoxanthine phosphoribosyltransferase. This is followed by a series of reactions to form TGNs, which are the major active metabolites. The cytotoxicity of azathioprine is due, in part, to the incorporation of TGNs into DNA.

Inactivation of 6-MP occurs via 2 major pathways: via methylation, which is catalyzed by TPMT, and via oxidation, which is catalyzed by xanthine oxidase (XO). In cells that have negligible XO levels (e.g., red blood cells), the TPMT activity is inversely correlated with TGN levels. And in individuals who take medicines that inhibit XO (e.g., allopurinol, used to manage gout), the level of azathioprine and its active metabolites may increase to a toxic level.

The NUDT15 enzyme also impacts TGN levels –– this enzyme is involved in the conversion of the active metabolites (TGNs) to inactive phosphorylated metabolites (1).

One of the most frequent adverse reactions to azathioprine is myelosuppression, which can occur in any individual and can typically be reversed by decreasing the dose of azathioprine. However, this risk increases in individuals who have reduced or absent TPMT and/or NUDT15 activity. (1).

Genetic testing to determine TPMT and NUDT15 genotype does not replace the need for regular complete blood count monitoring. One study reported that in individuals with IBD receiving thiopurine therapy, TPMT polymorphisms were associated with the overall incidence of adverse reactions and with bone marrow toxicity, but not with other adverse reactions such as liver damage and pancreatitis. Furthermore, TPMT and NUDT15 variants do not fully explain all cases of bone marrow suppression in individuals taking azathioprine. Therefore, regular blood tests to monitor for side effects are still needed during therapy (12, 13).

## Gene: TPMT

The TPMT gene encodes thiopurine S-methyltransferase, which is historically classified as a phase II metabolism enzyme. Importantly, TPMT is one of the main enzymes involved in the metabolism of thiopurines, such as azathioprine.

The TPMT gene is highly polymorphic, with over 40 reported variant star (*) alleles (14-17). The TPMT*1 allele is associated with normal enzyme activity (wild type).

The TPMT*1 is considered the wild-type allele when no variants are detected, and is associated with normal enzyme activity and the “normal metabolizer” phenotype. Individuals who are normal metabolizers are more likely to have a typical response to azathioprine and a low risk of myelosuppression; however, all individuals receiving azathioprine require close monitoring. (18-21).

Most individuals are TPMT normal metabolizers (~86–97%). Three variant TPMT alleles account for over 90% of the reduced or absent activity TPMT alleles (18, 19, 22):

- TPMT*2 (c.238G>C)
- TPMT*3A (c.460G>A and c.719A>G in cis)
- TPMT*3C (c.719A>G)

Individuals who are TPMT poor metabolizers (~ 0.3% of individuals of European or African ancestry) have 2 non-functional TPMT alleles (Table 4). When treated with standard doses of azathioprine, these individuals will universally experience life-threatening bone marrow suppression because of high levels of TGNs (1).

Individuals who are TPMT intermediate metabolizers (approximately 3–14% of the general population) are heterozygous with one no function TPMT allele. These individuals may also be unable to tolerate conventional doses of thiopurines due to increased levels of TGNs and are at an increased risk of moderate to severe bone marrow suppression. However, some of these individuals, approximately 40–70%, can tolerate the full dose of azathioprine. This may be because heterozygous-deficient individuals have lower concentrations of less active metabolites, such as methylmercaptopurine nucleotides, than homozygous-deficient individuals (18, 19).

Table 4.

Assignment of likely TPMT Phenotype based on Genotype (CPIC, 2018)

Likely phenotype^a^ | Genotype | Examples of diplotype
Normal metabolizer | An individual with 2 normal function alleles | *1/*1
Intermediate metabolizer | An individual with one normal function allele PLUS one no function allele | *1/*2, *1/*3A, *1/*3B, *1/*3C, *1/*4
Possible intermediate metabolizer | An individual with one uncertain/unknown function allele PLUS one no function allele | *2/*8, *3A/*7
Poor metabolizer | An individual with 2 no function alleles | *3A/*3A, *2/*3A, *3A/*3C, *3C/*4, *2/*3C, *3A/*4
Indeterminate | An individual with 2 uncertain/unknown function alleles OR one normal function allele plus one uncertain allele function allele | *6/*8 *1/*8

TPMT, thiopurine methyltransferase; NUDT15, Nudix (Nucleoside Diphosphate Linked Moiety X)-Type Motif 15

^a^ See TPMT and NUDT15 Frequency Table and Diplotype-Phenotype Table (3) for estimates of phenotype frequencies among different ethnic/geographic groups and for a more comprehensive list of predicted metabolizer phenotypes.

This CPIC table is adapted from (2).

The frequency of TPMT variant alleles vary among different ethnic populations. In the United States, the most common low-activity allele in the Caucasian population is TPMT*3A (~5%). This allele is also found in individuals who originate from India and Pakistan, but less frequently (14).

In East Asian, African-American, and some African populations, the most common variant is TPMT*3C (~2%), although TPMT*8 may be more common in African populations than previously thought (~2%). In general, TPMT*2 occurs much less commonly, and TPMT*3B occurs rarely (14, 23).

## Gene: NUDT15

The NUDT15 gene encodes an enzyme that belongs to the nudix hydrolase superfamily. Members of this superfamily catalyze the hydrolysis of nucleoside diphosphates, which are created as a result of oxidative damage (e.g., from treatment with drugs such as thiopurines).

Nudix hydrolase 15 is directly involved in the metabolism of thiopurines, as it catalyzes the conversion of active metabolites (TdGTP) to less toxic metabolites (TdGMP) and in doing so, prevents the incorporation of toxic metabolites into DNA (24).

In individuals with reduced or absent NUDT15 activity (intermediate or poor metabolizers, Table 5), the reduction in NUDT15-mediated degradation of TdGTP results in more TdGTP available for incorporation into DNA, leading to increased DNA damage and cell death. These individuals subsequently have increased sensitivity to thiopurines at standard doses, including an increased risk of severe myelosuppression (25).

Similar to TPMT, the NUDT15 gene is polymorphic, as the PharmVar (https://www.pharmvar.org/gene/NUDT15) Consortium currently has catalogued 21 variant alleles. However, most variants are rare, and the clinical significance of many NUDT15 star (*) alleles is currently unclear.

The first NUDT15 variant associated with thiopurine toxicity is p.R139C (rs116855232), which is present in both the NUDT15*2 and NUDT15*3 haplotypes. This amino acid change results in an unstable protein with almost no enzymatic activity. (25)

The FDA drug label for thioguanine cites one study of 1028 children with acute lymphoblastic leukemia, wherein the tolerated maintenance dose of the related drug, mercaptopurine, varied greatly, depending on the degree of deficiency in TPMT, or NUDT15, or both. Individuals who were heterozygous deficient for only one gene tolerated between 50–90% of the planned dosage. However, the tolerated dosage dropped to 30–50% of the planned dosage for individuals who were heterozygous deficient for both TPMT and NUDT15. Individuals who had bi-allelic deficiency of either TPMT or NUDT15 only tolerated 5–10% of the planned mercaptopurine dosage. (24, 26)

Deficiency of NUDT15 is rare among individuals with European or African ancestry (found in less than 1%); however, NUDT15 deficiency is more common among individuals with East Asian ancestry (e.g, Korea, China, Japan, Vietnam) (~ 2%) (2, 27, 28).

Table 5.

Assignment of likely NUDT15 Phenotype based on Genotype (CPIC, 2018)

Likely phenotype^a^ | Genotype | Examples of diplotype
Normal metabolizer | An individual with 2 normal function alleles | *1/*1
Intermediate metabolizer | An individual with one normal function allele PLUS one no function allele | *1/*2, *1/*3
Possible intermediate metabolizer | An individual with one uncertain/unknown function allele PLUS one no function allele | *2/*5, *3/*6
Poor metabolizer | An individual with 2 no function alleles | *2/*2, *2/*3, *3/*3
Indeterminate | An individual with 2 uncertain function alleles OR one normal function allele plus one uncertain function allele | *1/*4, *1/*5 *4/*5, *5/*6

TPMT, thiopurine methyltransferase; NUDT15, Nudix (Nucleoside Diphosphate Linked Moiety X)-Type Motif 15

^a^ See TPMT and NUDT15 Frequency Table and Diplotype-Phenotype Table (3) for estimates of phenotype frequencies among different ethnic/geographic groups and for a more comprehensive list of predicted metabolizer phenotypes.

This CPIC table is adapted from (2).

## Linking Gene Variation with Treatment Response

Genetic variation in the TPMT and NUDT15 genes strongly influences the safety of thiopurine therapy, specifically, influencing the risk of treatment-related bone marrow suppression (29).

Thiopurine methyltransferase deficiency is the primary genetic cause of thiopurine intolerance in Europeans and Africans, and NUDT15 deficiency is a more common cause in Asians and Hispanics.

The clinical impact of variant NUDT15 alleles was discovered more recently than for TPMT, and there is less evidence available to guide dose adjustments. However, there currently is one clinical trial in progress that addresses azathioprine dosing guided by the status of both TPMT and NUDT15 expression, for the treatment of IBD (5, 30-32).

Currently, TPMT and NUDT15 testing is not required by the FDA before starting treatment with any thiopurine (azathioprine, mercaptopurine, or thioguanine); however, both genes were listed in the recently published FDA Association tables as pharmacogenetics associations with data supporting therapeutic management recommendations (33). Consequently, routine genotyping for TPMT and NUDT15 polymorphisms has not been universally adopted (34).

## Genetic Testing

The NIH Genetic Testing Registry, GTR (https://www.ncbi.nlm.nih.gov/gtr/), displays genetic tests that are currently available for the azathioprine (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=azathioprine) drug response, and the genes TPMT (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=TPMT) and NUDT15 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=nudt15). The genes may be tested separately, or together, as part of a test panel that evaluates the drug response to thiopurines.

As with many commercial tests, only the most common variants are usually tested for (e.g., for TPMT, the *2, *3A, and *3C allele, which accounts for more than 90% of known inactivating alleles). This means that rare and/or previously undiscovered variants will not be detected by variant-specific genotyping methods (18, 19, 35-38).

It is important to note that for TPMT*3A, 2 variants, c.460G>A and c.719A>G, are in cis. The variant, c.460G>A by itself is TPMT*3B and c.719A>G by itself is TPMT*3C. Most clinical laboratories are unable to phase the 2 variants. In most cases, especially if the individual is of European ancestry, the laboratory will assume the 2 variants are in cis, though the possibility of the variants being in trans cannot be ruled out.

Phenotype testing is also available for TPMT. Phenotype tests directly measure TPMT enzyme activity in red blood cells, but accurate phenotyping is not possible in individuals who have recently received blood transfusions (20). However, one study reported that TPMT genotyping was more reliable than phenotyping in identifying individuals at risk of adverse reactions from thiopurine treatment, and several studies reported that the TPMT genotype is a better indicator than TPMT activity for predicting TGN accumulation or treatment outcome (21, 39-41).

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2020 Statement from the US Food and Drug Administration (FDA):

Genetic polymorphisms influence TPMT and NUDT15 activity. Several published studies indicate that patients with reduced TPMT or NUDT15 activity receiving usual doses of 6-MP or azathioprine, accumulate excessive cellular concentrations of active 6-TGNs, and are at higher risk for severe myelosuppression. Because of the risk of toxicity, patients with TPMT or NUDT15 deficiency require alternative therapy or dose modification.

Approximately 0.3% (1:300) of patients of European or African ancestry have two loss-of-function alleles of the TPMT gene and have little or no TPMT activity (homozygous deficient or poor metabolizers), and approximately 10% of patients have one loss-of-function TPMT allele leading to intermediate TPMT activity (heterozygous deficient or intermediate metabolizers). The TPMT*2, TPMT*3A, and TPMT*3C alleles account for about 95% of individuals with reduced levels of TPMT activity. NUDT15 deficiency is detected in <1% of patients of European or African ancestry. Among patients of East Asian ancestry (i.e., Chinese, Japanese, Vietnamese), 2% have two loss-of-function alleles of the NUDT15 gene, and approximately 21% have one loss-of-function allele. The p.R139C variant of NUDT15 (present on the *2 and *3 alleles) is the most commonly observed, but other less common loss-of-function NUDT15 alleles have been observed.

[…]

Patients with thiopurine S-methyl transferase (TPMT) or nucleotide diphosphatase (NUDT15) deficiency may be at an increased risk of severe and life-threatening myelotoxicity if receiving conventional doses of azathioprine. Death associated with pancytopenia has been reported in patients with absent TPMT activity receiving azathioprine. In patients with severe myelosuppression, consider evaluation for TPMT and NUDT15 deficiency. Consider alternative therapy in patients with homozygous TPMT or NUDT15 deficiency and reduced dosages in patients with heterozygous deficiency.

[…]

TPMT and NUDT15 Testing: Consider genotyping or phenotyping patients for TPMT deficiency and genotyping for NUDT15 deficiency in patients with severe myelosuppression. TPMT and NUDT15 testing cannot substitute for complete blood count (CBC) monitoring in patients receiving azathioprine. Accurate phenotyping (red blood cell TPMT activity) results are not possible in patients who have received recent blood transfusions.

[…]

Patients with TPMT and/or NUDT15 Deficiency

Consider testing for TPMT and NUDT15 deficiency in patients who experience severe bone marrow toxicities. Early drug discontinuation may be considered in patients with abnormal CBC results that do not respond to dose reduction.

Homozygous deficiency in either TPMT or NUDT15 Because of the risk of increased toxicity, consider alternative therapies for patients who are known to have TPMT or NUDT15 deficiency.

Heterozygous deficiency in TPMT and/or NUDT15 Because of the risk of increased toxicity, dosage reduction is recommended in patients known to have heterozygous deficiency of TPMT or NUDT15. Patients who are heterozygous for both TPMT and NUDT15 deficiency may require more substantial dosage reductions.

Please review the complete therapeutic recommendations that are located here: (1).

### 2018 Statement from the Clinical Pharmacogenetics Implementation Consortium (CPIC)

TPMT recommendation

If starting doses are already high (e.g., 75 mg/m^2^ of mercaptopurine), as is true in some ALL treatment regimens, lower than normal starting doses should be considered in TPMT intermediate metabolizers and markedly reduced doses (10-fold reduction) should be used in TPMT poor metabolizers. This approach has decreased the risk of acute toxicity without compromising relapse rate in ALL. Even at these markedly reduced dosages, erythrocyte TGN concentrations in TPMT poor metabolizers remain well above those tolerated and achieved by the majority of patients (who are TPMT normal metabolizers).

In some nonmalignant conditions, alternative agents may be chosen for TPMT intermediate or poor metabolizers rather than reduced doses of thiopurines; if thiopurines are used, full starting doses are recommended for TPMT normal metabolizers, reduced doses (30–80% of target dose) in TPMT intermediate metabolizers, and substantially reduced doses (or use of an alternative agent) in TPMT poor metabolizers.

Some of the clinical data upon which dosing recommendations are based rely on measures of TPMT phenotype rather than genotype; however, because TPMT genotype is strongly linked to TPMT phenotype, these recommendations apply regardless of the method used to assess TPMT status.

NUDT15 recommendation

Similar to TPMT, tolerated mercaptopurine dosage is also correlated with the number of nonfunctional alleles of the NUDT15 gene. In fact, the degree of thiopurine intolerance (e.g., for mercaptopurine) is largely comparable between carriers of TPMT vs. NUDT15 decreased function alleles, there remains a paucity of multi-ethnic studies examining both TPMT and NUDT15 variants.

Therefore, our NUDT15 recommendations parallel those for TPMT. For NUDT15 normal metabolizers (NUDT15*1/*1), starting doses do not need to be altered. For NUDT15 intermediate metabolizers (e.g., NUDT15*1/*3), reduced starting doses should be considered to minimize toxicity, particularly if the starting doses are high (e.g., 75 mg/m^2^/ day for mercaptopurine). For NUDT15 poor metabolizers (e.g., NUDT15*3/*3), substantially reduced doses (e.g., 10 mg/m^2^/ day of mercaptopurine) or the use of an alternative agent should be considered.

As for TPMT, there is substantial variability in the tolerated thiopurine dosages within NUDT15 intermediate metabolizers, with a minority of individuals who do not seem to require significant dose reduction. Therefore, genotype-guided prescribing recommendations apply primarily to starting doses; subsequent dosing adjustments should be made based on close monitoring of clinical myelosuppression (or disease-specific guidelines). In contrast, a full dose of mercaptopurine poses a severe risk of prolonged hematopoietic toxicity in NUDT15 poor metabolizers and pre-emptive dose reductions are strongly recommended.

The NUDT15 poor metabolizer phenotype is observed at a frequency of about 1 in every 50 patients of East Asian descent, which is more common than the TPMT poor metabolizer phenotype in Europeans, and, thus, genotyping NUDT15 in the Asian populations may be of particular clinical importance. NUDT15 deficiency is also more prevalent in individuals of Hispanic ethnicity, particularly those with high levels of Native American genetic ancestry.

Please review the complete therapeutic recommendations, which include CPIC’s recommended course of action if both TPMT and NUDT15 genotypes are known, located here: (2).

### 2019 Summary of recommendations from the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

The Dutch Pharmacogenetics Working Group considers genotyping before starting azathioprine or 6-mercaptopurine to be essential for drug safety. Genotyping must be performed before drug therapy has been initiated to guide drug and dose selection.

TPMT Intermediate Metabolizer

Grade 2 leukopenia occurs in 23% of these patients with normal therapy for immunosuppression. The genetic variation increases the quantity of the active metabolites of azathioprine and mercaptopurine.

Recommendation:

IMMUNOSUPPRESSION

- Start with 50% of the standard dose

Adjustment of the initial dose should be guided by toxicity (monitoring of blood counts) and effectiveness.

Dose adjustment is not required for doses lower than 1.5 mg/kg per day for azathioprine or 0.75 mg/kg per day for mercaptopurine.

LEUKEMIA

- Start with 50% of the standard mercaptopurine dose, or start with the standard dose and reduce to 50% if side effects necessitate a dose reduction

It is not known whether dose reduction in advance results in the same efficacy as dose reduction based on toxicity.

The initial dose should be adjusted based on toxicity (monitoring of the blood counts) and efficacy.

Note: more stringent dose reductions are necessary if the patient is also NUDT15 IM or NUDT15 PM.

TPMT Poor Metabolizer

Grade 2 leukopenia and intolerance occurred in 98% of these patients with standard therapy. The gene variation increases the quantities of the active metabolites of azathioprine and mercaptopurine.

Recommendation:

- Choose an alternative or use 10% of the standard dose.

Any adjustment of the initial dose should be guided by toxicity (monitoring of blood counts) and effectiveness.

If the dose is decreased: advise patients to seek medical attention when symptoms of myelosuppression (such as severe sore throat in combination with fever, regular nosebleeds and tendency to bruising) occur

Background information:

Azathioprine is converted in the body to mercaptopurine. Mercaptopurine is an inactive pro-drug, which is converted to the active metabolites - thioguanine nucleotides - in the body.

Two catabolic routes reduce mercaptopurine bio-availability for thioguanine nucleotide formation. Thiopurine methyltransferase (TPMT) catalyses S-methylation of both mercaptopurine and the 6- mercaptopurine ribonucleotides formed in the metabolic pathway. In addition to this, mercaptopurine is oxidised to the inactive 6-thiouric acid by the enzyme xanthine oxidase (XO), which occurs primarily in the liver and intestines.

For more information about the TPMT phenotypes: see the general background information about TPMT on the KNMP Knowledge Bank or on www.knmp.nl (search for TPMT).

NUDT15 Intermediate Metabolizer

Grade ≥ 2 leukopenia occurs in 42% of these patients with standard immunosuppression therapy. The gene variation increases the concentration of the fully activated metabolite of azathioprine and mercaptopurine.

IMMUNOSUPPRESSION

- start with 50% of the standard dose

Adjustment of the initial dose should be performed based on toxicity (monitoring of the blood counts) and efficacy.

LEUKEMIA

- start at 50% of the standard mercaptopurine dose, or start with the standard dose and reduce to 50% if side effects necessitate a dose reduction

It is not known whether dose reduction in advance results in the same efficacy as dose reduction based on toxicity.

Adjustment of the initial dose should be performed based on toxicity (monitoring of the blood counts) and efficacy.

Note: more stringent dose reductions are necessary if the patient is also TPMT IM or TPMT PM.

NUDT15 Poor Metabolizer

Grade ≥ 2 leukopenia occurs in 96% of these patients with standard therapy. The gene variation increases the concentration of the fully activated metabolite of azathioprine and mercaptopurine.

- avoid azathioprine and mercaptopurine
- if it is not possible to avoid azathioprine and mercaptopurine: use 10% of the standard dose and advise patients to seek medical attention when symptoms of myelosuppression (such as severe sore throat in combination with fever, regular nosebleeds and tendency to bruising) occur

Any adjustment of the initial dose should be guided by toxicity (monitoring of blood counts) and efficacy.

Background information:

NUDT15 reverses the last step in the formation of the active metabolite of mercaptopurine and its precursor azathioprine. It converts 6-thiodeoxyguanosine triphosphate (6-thio-dGTP), which is incorporated in DNA, to 6-thiodeoxyguanosine monophosphate (6-thio-dGMP). Lower metabolic activity of NUDT15 therefore leads to increased intracellular concentrations of the active metabolite 6- thio-dGTP. This increases the risk of side effects, such as myelosuppression.

For more information about TPMT and NUDT15 phenotypes: see the general background information in the KNMP Knowledge Bank or on www.knmp.nl (search for TPMT or NUDT15).

Please review the complete therapeutic recommendations that are located here: (3, 4).

## Nomenclature for Selected TPMT and NUDT15 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
TPMT*2 | 238G>C Ala80Pro | NM_000367.2:c.238G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/12721/) | NP_000358.1:p.Ala80Pro (https://www.ncbi.nlm.nih.gov/clinvar/variation/12721/) | rs1800462 (https://www.ncbi.nlm.nih.gov/snp/rs1800462)
TPMT*3A | This allele contains 2 variants in cis: c.460G>A and c.719A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/12722/)
TPMT*3B | 460G>A Ala154Thr | NM_000367.2:c.460G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/37126/) | NP_000358.1:p.Ala154Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/37126/) | rs1800460 (https://www.ncbi.nlm.nih.gov/snp/rs1800460)
TPMT*3C | 719A>G Tyr240Cys | NM_000367.2:c.719A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/12725/) | NP_000358.1:p.Tyr240Cys (https://www.ncbi.nlm.nih.gov/clinvar/variation/12725/) | rs1142345 (https://www.ncbi.nlm.nih.gov/snp/rs1142345)
NUDT15*3 | p.R139C c.415C>T | NM_018283.4:c.415C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/225201/) | NP_060753.1:p.Arg139Cys (https://www.ncbi.nlm.nih.gov/clinvar/variation/225201/) | rs116855232 (https://www.ncbi.nlm.nih.gov/snp/rs116855232)

Note: the p.R139C variant of nudix hydrolase 15 (NUDT15) is present on the NUDT15*2 and NUDT15*3 alleles.

The TPMT Nomenclature Committee (https://liu.se/en/research/tpmt-nomenclature-committee) defines the nomenclature and numbering of novel thiopurine methyltransferase (TPMT) variants.

Nomenclature for NUDT15 is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (42))

## Acknowledgments

The author would like to thank Cecilia P. Chung, MD, MPH, Associate Professor of Medicine, Vanderbilt University Medical Center, Nashville, TN, USA; and Bernard Esquivel, MD, PhD, MHA, President of the Latin American Association for Personalized Medicine, Vancouver, BC, Canada, for reviewing this summary.

Second Edition:

The author would like to thank Stuart A. Scott, Assistant Professor of Genetics and Genomic Sciences, Icahn School of Medicine at Mount Sinai, New York, NY, USA; for reviewing this summary.

First Edition:

The author would like to thank the Pharmacogenomics Knowledgebase, PharmGKB (http://www.pharmgkb.org/), and the Clinical Pharmacogenetics Implementation Consortium, CPIC (http://www.pharmgkb.org/page/cpic).

## Version History

To view an earlier version of this summary, please see:

Update: May 03, 2016

Update: March 18, 2013

## References

1 AZATHIOPRINE tablet [package insert]. Parsippany, NJ. Ascend; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=bc6dc4bd-2121-4613-9d90-4a504010c98a.
2 Relling M.V., et al. (2019). Clinical Pharmacogenetics Implementation Consortium Guideline for Thiopurine Dosing Based on TPMT and NUDT15 Genotypes: 2018 Update. Clin Pharmacol Ther.
3 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. NUDT15: azathioprine/ 6-mercaptopurine [Cited Dec 2019]. Available from: https://www.knmp.nl/media/1058
4 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharamcogenetic Guidelines [Internet]. Netherlands. TPMT: azathioprine/6-mercaptopurine [Cited Dec 2019]. Available from: https://www.knmp.nl/media/1058
5 Marinaki A.M., Arenas-Hernandez M. (2020). Reducing risk in thiopurine therapy. Xenobiotica.
6 Huang P.W., Tseng Y.H., Tsai T.F. (2020). Predictive Value of NUDT15 Variants on Neutropenia Among Han Chinese Patients with Dermatologic Diseases: A Single-Center Observational Study. Dermatol Ther (Heidelb).
7 Prefontaine E., Macdonald J.K., Sutherland L.R. (2009). Azathioprine or 6-mercaptopurine for induction of remission in Crohn's disease. Cochrane Database Syst Rev.
8 Vilien M., et al. (2004). Randomized controlled azathioprine withdrawal after more than two years treatment in Crohn's disease: increased relapse rate the following year. Aliment Pharmacol Ther.
9 Treton X., et al. (2009). Azathioprine withdrawal in patients with Crohn's disease maintained on prolonged remission: a high risk of relapse. Clin Gastroenterol Hepatol.
10 Kotlyar D.S., et al. (2015). Risk of lymphoma in patients with inflammatory bowel disease treated with azathioprine and 6-mercaptopurine: a meta-analysis. Clin Gastroenterol Hepatol.
11 Khan N., et al. (2013). Risk of lymphoma in patients with ulcerative colitis treated with thiopurines: a nationwide retrospective cohort study. Gastroenterology.
12 Liu Y.P., et al. (2015). Association between thiopurine S-methyltransferase polymorphisms and thiopurine-induced adverse drug reactions in patients with inflammatory bowel disease: a meta-analysis. PLoS One.
13 MERCAPTOPURINE- mercaptopurine tablet [package insert]. Spring Valley, NY. Par Phamaceutical Companies; 2015. Available from: http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=40b09616-5bb1-4ef8-98cd-d87537254296.
14 Wang L., et al. (2010). Very important pharmacogene summary: thiopurine S-methyltransferase. Pharmacogenet Genomics.
15 Katara P., Kuntal H. (2016). TPMT Polymorphism: When Shield Becomes Weakness. Interdiscip Sci.
16 Schaeffeler E., et al. (2004). Comprehensive analysis of thiopurine S-methyltransferase phenotype-genotype correlation in a large population of German-Caucasians and identification of novel TPMT variants. Pharmacogenetics.
17 Gaedigk A., et al. (2017). Prediction of CYP2D6 phenotype from genotype across world populations. Genet Med.
18 Relling M.V., et al. (2011). Clinical Pharmacogenetics Implementation Consortium guidelines for thiopurine methyltransferase genotype and thiopurine dosing. Clin Pharmacol Ther.
19 Relling M.V., et al. (2013). Clinical pharmacogenetics implementation consortium guidelines for thiopurine methyltransferase genotype and thiopurine dosing: 2013 update. Clin Pharmacol Ther.
20 DiPiero J., Teng K., Hicks J.K. (2015). Should thiopurine methyltransferase (TPMT) activity be determined before prescribing azathioprine, mercaptopurine, or thioguanine?. Cleve Clin J Med.
21 Lennard L., et al. (2015). Thiopurine dose intensity and treatment outcome in childhood lymphoblastic leukaemia: the influence of thiopurine methyltransferase pharmacogenetics. Br J Haematol.
22 McLeod H.L., Siva C. (2002). The thiopurine S-methyltransferase gene locus -- implications for clinical pharmacogenomics. Pharmacogenomics.
23 Tai H.L., et al. (1996). Thiopurine S-methyltransferase deficiency: two nucleotide transitions define the most prevalent mutant allele associated with loss of catalytic activity in Caucasians. Am J Hum Genet.
24 Yang J.J., et al. (2015). Inherited NUDT15 variant is a genetic determinant of mercaptopurine intolerance in children with acute lymphoblastic leukemia. J Clin Oncol.
25 Yang S.K., et al. (2014). A common missense variant in NUDT15 confers susceptibility to thiopurine-induced leukopenia. Nat Genet.
26 TABLOID - thioguanine tablet [package insert]. Mauritius. Aspen Global Inc.; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=4490128b-e73f-4849-9d6e-e8591639d771.
27 Chang J.Y., et al. (2020). Genotype-based Treatment With Thiopurine Reduces Incidence of Myelosuppression in Patients With Inflammatory Bowel Diseases. Clin Gastroenterol Hepatol.
28 Chang J.Y., Cheon J.H. (2019). Thiopurine Therapy in Patients With Inflammatory Bowel Disease: A Focus on Metabolism and Pharmacogenetics. Dig Dis Sci.
29 Anandi P., et al. (2020). Combining clinical and candidate gene data into a risk score for azathioprine-associated leukopenia in routine clinical practice. Pharmacogenomics J.
30 Koutsilieri S., et al. (2019). Optimizing thiopurine dosing based on TPMT and NUDT15 genotypes: It takes two to tango. Am J Hematol.
31 Wahlund M., et al. (2020). The Role of TPMT, ITPA, and NUDT15 Variants during Mercaptopurine Treatment of Swedish Pediatric Patients with Acute Lymphoblastic Leukemia. J Pediatr.
32 Tailored Therapeutic Model According to the Expression of Genes in Inflammatory Bowel Disease Patients. 2018 25 October 2018 [cited 2020; Available from: https://clinicaltrials.gov/ct2/show/NCT03719118.
33 Table of Pharmacogenetic Associations. 2020 25 February 2020; Available from: https://www.fda.gov/medical-devices/precision-medicine/table-pharmacogenetic-associations.
34 Simeonidis S., et al. (2019). Application of Economic Evaluation to Assess Feasibility for Reimbursement of Genomic Testing as Part of Personalized Medicine Interventions. Front Pharmacol.
35 Roberts R.L., et al. (2014). Identification of a novel thiopurine S-methyltransferase allele (TPMT*37). Pharmacogenet Genomics.
36 Appell M.L., et al. (2013). Nomenclature for alleles of the thiopurine methyltransferase gene. Pharmacogenet Genomics.
37 Landy J., et al. (2011). Novel thiopurine methyltransferase variant TPMT*28 results in a misdiagnosis of TPMT deficiency. Inflamm Bowel Dis.
38 Matimba A., et al. (2014). Thiopurine pharmacogenomics: association of SNPs with clinical response and functional validation of candidate genes. Pharmacogenomics.
39 Gonzalez-Lama Y., et al. (2011). Thiopurine methyl-transferase activity and azathioprine metabolite concentrations do not predict clinical outcome in thiopurine-treated inflammatory bowel disease patients. Aliment Pharmacol Ther.
40 Lennard L., et al. (2013). Thiopurine methyltransferase genotype-phenotype discordance and thiopurine active metabolite formation in childhood acute lymphoblastic leukaemia. Br J Clin Pharmacol.
41 Konidari A., et al. (2014). Thiopurine monitoring in children with inflammatory bowel disease: a systematic review. Br J Clin Pharmacol.
42 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al. HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016.37(6): p.564-9.26931183

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance to nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

## Related Summaries by Gene

Mercaptopurine Therapy and TPMT and NUDT15 Genotype

Thioguanine Therapy and TPMT and NUDT15 Genotype

## Related Summaries by Drug Class

Mercaptopurine Therapy and TPMT and NUDT15 Genotype

Thioguanine Therapy and TPMT and NUDT15 Genotype

## Tests in GTR by Condition

Azathioprine response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN077959&term=CN077959[DISCUI]&display_string=Azathioprine response)

## Tests in GTR by Gene

TPMT gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=7172[geneid]+AND+CN077959[cui])

NUDT15 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=55270[geneid]+AND+CN077959[cui])