# Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

## Introduction

Amitriptyline is a tricyclic antidepressant used in the treatment of several psychiatric disorders, including major depression, obsessive-compulsive disorder, panic attacks, generalized anxiety disorder, post-traumatic stress disorder, and bulimia. Amitriptyline also has different off-label uses, including migraine prevention, neuropathic pain management, fibromyalgia, and enuresis (bedwetting) (1).

Tricyclic antidepressants (TCAs) primarily mediate their therapeutic effect by inhibiting the reuptake of both serotonin and norepinephrine, leaving more neurotransmitter in the synaptic cleft stimulating the neuron. Given that the tricyclics can also block different receptors (H1 histamine, α1-adrenergic, and muscarinic receptors), side effects are common. As such, selective serotonin reuptake inhibitors (SSRIs) have largely replaced the use of TCAs; however, TCAs still have an important use in specific types of depression and other conditions.

Amitriptyline is metabolized mainly via CYP2C19 and CYP2D6 pathways. Metabolism by CYP2C19 results in active metabolites, including nortriptyline, which is also a tricyclic antidepressant. Metabolism catalyzed by CYP2D6 results in the formation of the less active 10-hydroxy metabolite. Both the CYP2D6 and CYP2C19 genes are highly polymorphic, resulting in proteins with different enzyme activity or expression levels. Individuals who are CYP2D6 “ultrarapid metabolizers” (UM) have more than 2 normal function alleles (multiple copies), whereas CYP2C19 UM have 2 increased function alleles. Individuals who are CYP2D6 or CYP2C19 “poor metabolizers” (PM) have 2 no function alleles for CYP2D6 or CYP2C19.

The FDA-approved drug label for amitriptyline states that CYP2D6 PM have higher than expected plasma concentrations of tricyclic antidepressants when given usual doses. The FDA recommendations also include monitoring tricyclic antidepressant plasma levels whenever a tricyclic antidepressant is co-administered with another drug known to be an inhibitor of CYP2D6 (Table 1) (1).

The Dutch Pharmacogenetic Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP) have issued recommendations for altered dosing based on CYP2D6 metabolizer phenotype (Table 2) (2, 3). Individuals who are CYP2D6 UM may require up to 1.6 times the normal dose, though cardiac toxicity risk may indicate use of an antidepressant that is less dependent upon CYP2D6 metabolism, such as citalopram or sertraline. Dose reductions are recommended for CYP2D6 intermediate metabolizer (IM) individuals (75% of normal dose) and CYP2D6 PM individuals (60% of normal dose), along with monitoring for side effects and plasma drug levels. (3). The DPWG does not recommend any changes in dosing based on CYP2C19 metabolizer status, since the combined dose of amitriptyline and the active metabolite nortriptyline are not significantly impacted. (2)

In 2016, the Clinical Pharmacogenetics Implementation Consortium (CPIC) published dosing recommendations for tricyclic antidepressants based on CYP2C19 and CYP2D6 metabolizer status, either individually or in combination (Table 3, Table 4) (4). For CYP2D6 UM, CPIC recommends avoiding the use of a tricyclic due to the potential lack of efficacy, and to consider an alternative drug not metabolized by CYP2D6. If a TCA is still warranted, CPIC recommends considering titrating the TCA to a higher target dose (compared with CYP2D6 normal metabolizers, “NM”) and using therapeutic drug monitoring to guide dose adjustments. For CYP2D6 IM, CPIC recommends considering a 25% reduction of the starting dose, and for CYP2D6 PM, to avoid the use of tricyclics because of the potential for side effects. If a tricyclic is still warranted for CYP2D6 PM, CPIC recommends considering a 50% reduction of the starting dose while monitoring drug plasma concentrations to avoid side effects.

For CYP2C19 UM, CPIC recommends avoiding the use of tertiary amines (for example, amitriptyline) due to the potential for a sub-optimal response, and to consider an alternative drug not metabolized by CYP2C19, such as the secondary amines nortriptyline or desipramine. For CYP2C19 PMs, CPIC recommends avoiding tertiary amine use due to the potential for sub-optimal response, and to consider an alternative drug not metabolized by CYP2C19. If a tertiary amine is still warranted for CYP2C19 PMs, CPIC recommends considering a 50% reduction of the starting dose while monitoring drug plasma concentrations to avoid side effects (4). For gene-based dosing of TCAs for neuropathic pain, where the initial doses are lower, CPIC does not recommend dose modifications for PMs or IMs (either CYP2D6 or CYP2C19). For CYP2D6 UM individuals, CPIC optionally recommends considering an alternative medication due to a higher risk of therapeutic failure of TCAs for neuropathic pain (4).

Table 1:

CYP2D6 Status and Amitriptyline Therapy Management, FDA 2023

CYP2D6 status | Clinical impact | Recommended action
UM or IM | May alter systemic concentrations. | (None)
PM | Higher than expected plasma concentrations when given usual doses | (None)
Any individual with stable TCA therapy with CYP2D6 inhibitor co-medication | May become abruptly toxic when given a new CYP2D6 inhibitor as concomitant therapy | May require lower doses than usually prescribed for either TCA or the other drug; monitor TCA plasma levels whenever a TCA is co-administered with a known CYP2D6 inhibitor

UM: Ultrarapid metabolizer; IM: Intermediate metabolizer; PM: Poor metabolizer; TCA: Tricyclic Antidepressant

Table adapted from (1, 5).

Table 2:

CYP Metabolizer Status and Amitriptyline Therapy Recommendations, DPWG 2023

CYP status | Clinical impact | Recommended action
CYP2D6 UM | The risk of ineffectiveness is increased and the risk of cardiotoxic side effects may be increased. The gene variation leads to increased conversion of amitriptyline and the active metabolite nortriptyline to less active and inactive metabolites. | Increase the dose to 1.6 times the normal dose, monitor the effect and side effects or the plasma concentrations and be alert to increased plasma concentrations of the cardiotoxic Z-10-hydroxy metabolites. Plasma concentrations of Z-hydroxy nortriptyline or Z-hydroxy amitriptyline higher than 40 ng/mL are considered toxic. If a dose increase is not desirable due to the cardiotoxic hydroxy metabolite: avoid amitriptyline. Anti-depressants that are not metabolized by CYP2D6, or to a lesser extent, include citalopram and sertraline.
CYP2D6 IM | The risk of side effects is increased, because the gene variation leads to increased plasma concentrations of the active metabolite nortriptyline and to a lesser extent of amitriptyline. | Use 75% of the normal dose and monitor the efficacy and side effects or the plasma concentrations of amitriptyline and nortriptyline to adjust the maintenance dose..
CYP2D6 PM | In theory, risk of side effects is increased, because the genetic variation results in higher plasma concentrations of the active metabolite nortriptyline and to a lesser extent of amitriptyline. | Use 60% of the normal dose and monitor the effect and side effects or the plasma concentrations of amitriptyline and nortriptyline to adjust the maintenance dose
CYP2C19 IM or PM | The gene variation has an effect on the exposure to amitriptyline, but not on the exposure to amitriptyline + the active metabolite nortriptyline, which determines the effect and side effects. | No action is required for this gene-drug interaction.
CYP2C19 UM | The gene variation decreases the exposure to amitriptyline and increases the exposure to the active metabolite nortriptyline, but there is no evidence to indicate that this results in an increase in side effects or a decrease in efficacy. | No action is required for this gene-drug interaction.

UM: Ultrarapid metabolizer; NM: normal metabolizer; IM: Intermediate metabolizer; PM: Poor metabolizer

Adapted from (2, 3)

Table 3:

CYP Metabolizer Status and Tricyclic Antidepressant Therapy Recommendations, CPIC 2016

CYP status^a^ | Clinical impact | Recommended action | Classification of recommendation for amitriptyline
CYP2D6 UM | Increased metabolism of TCAs to less active compounds compared with NM. Lower plasma concentrations of active drug will increase probability of pharmacotherapy failure | Avoid TCA or consider an alternate drug that is not metabolized by CYP2D6. If no alternate medication available, titrate to higher dose and use TDM to guide dosing. | Strong
CYP2D6 NM | Normal metabolism of TCAs | Initiate therapy with recommended starting dose | Strong
CYP2D6 IM | Reduced metabolism of TCAs to less active compounds compared with NM. Higher plasma concentrations of active drug will increase the probability of side effects | Consider a 25% reduction of recommended starting dose. Utilize TDM to guide dose adjustments. | Moderate
CYP2D6 AS = 1 | Reduced metabolism of TCAs to less active compounds compared with NM. Higher plasma concentrations of active drug will increase the probability of side effects | Consider a 25% reduction of recommended starting dose. Utilize TDM to guide dose adjustments. | Optional ^b^
CYP2D6 PM | Greatly reduced metabolism of TCAs to less active compounds compared with NM. Higher plasma concentrations of active drug will increase the probability of side effects | Avoid TCA use due to potential for side effects. Consider alternative drug not metabolized by CYP2D6. If a TCA is warranted, consider a 50% reduction of recommended starting dose. Utilize TDM to guide dose adjustments | Strong
CYP2C19 UM/RM | Increased metabolism of tertiary amines compared with normal metabolizers Greater conversion of tertiary amines to secondary amines may affect response or side effects | Avoid tertiary amine use due to potential for sub-optimal response. Consider alternative drug not metabolized by CYP2C19. TCAs without major CYP2C19 metabolism include the secondary amines nortriptyline and desipramine. If a tertiary amine is warranted, utilize TDM to guide dose adjustments | Optional
CYP2C19 NM/IM | Normal or reduced metabolism of tertiary amines. | Initiate therapy with recommended starting dose. | Strong
CYP2C19 PM | Greatly reduced metabolism of tertiary amines compared with normal metabolizers | Avoid tertiary amine use due to potential for sub-optimal response. Consider alternative drug not metabolized by CYP2C19. TCAs without major CYP2C19 metabolism include the secondary amines nortriptyline and desipramine. For tertiary amines, consider a 50% reduction of the recommended starting dose. Utilize TDM to guide dose adjustments | Optional

UM: Ultrarapid metabolizer; RM: Rapid metabolizer; NM: normal metabolizer; IM: Intermediate metabolizer; PM: Poor metabolizer; TCA: tricyclic antidepressant; TDM: therapeutic drug monitoring

^a^ There is limited evidence to guide dosage for non-normal metabolizer status for both CYP2D6 and CYP2C19 in the same individual; TDM is recommended to guide dosing for these individuals.

^b^ This recommendation from a 2019 Update by CPIC (6).

Table adapted from (4).

Table 4:

Dosing Recommendations for TCA with both CYP2D6 and CYP2C19 Phenotypes (CPIC, 2016)

Phenotype | CYP2D6 UM | CYP2D6 NM | CYP2D6 IM | CYP2D6 PM
CYP2C19 UM or RM | Avoid amitriptyline use ^1^ | Consider alternative drug not metabolized by CYP2C19 ^1^ | Consider alternative drug not metabolized by CYP2C19 ^1^ | Avoid amitriptyline use ^1^
CYP2C19 NM | Avoid amitriptyline use. If amitriptyline is warranted, consider titrating to a higher target dose (compared with NM) ^2^ | Initiate therapy with recommended starting dose ^2^ | Consider a 25% reduction of recommended starting dose ^3^ | Avoid amitriptyline use. If amitriptyline is warranted, consider a 50% reduction of recommended starting dose ^2^
CYP2C19 IM | Avoid amitriptyline use ^1^ | Initiate therapy with recommended starting dose ^2^ | Consider a 25% reduction of recommended starting dose ^1^ | Avoid amitriptyline use. If amitriptyline is warranted, consider a 50% reduction of recommended starting dose ^1^
CYP2C19 PM | Avoid amitriptyline use ^1^ | Avoid amitriptyline use. If amitriptyline is warranted, consider a 50% reduction of recommended starting dose ^3^ | Avoid amitriptyline use ^1^ | Avoid amitriptyline use ^1^

UM: Ultrarapid metabolizer; NM: normal metabolizer; IM: Intermediate metabolizer; PM: Poor metabolizer; TCA: tricyclic antidepressant; CPIC: Clinical Pharmacogenetics Implementation Consortium

^1^ Strength of recommendation: optional

^2^ Strength of recommendation: strong

^3^ Strength of recommendation: moderate

Table adapted from (4).

## Drug Class: Tricyclic Antidepressants

Tricyclic antidepressants (TCAs) are mixed serotonin-norepinephrine reuptake inhibitors. They increase the amount of neurotransmitter in the synaptic cleft, a mechanism thought to mediate their antidepressant effects.

From the 1960s to the 1980s, tricyclics were the first-line treatment for depression, until the introduction of SSRIs, which have fewer side effects and are considered more safe. The common side effects of tricyclics include anticholinergic side effects (for example, blurred vision, dry mouth, constipation, and sedation), cardiac effects, and orthostatic hypotension.

Today, the main therapeutic use of tricyclics is chronic pain management, such as neuropathic pain. However, tricyclics are still used to treat depression (especially treatment-resistant depression) as well as other psychiatric disorders, including obsessive–compulsive disorder, panic attacks, generalized anxiety disorder, post-traumatic stress disorder, bulimia nervosa, smoking cessation, and enuresis (bedwetting).

Tricyclics are named after their chemical structure of 3 central rings and a side chain important for its function and activity. This structure determines whether a drug is classified a tertiary amine (amitriptyline, clomipramine, doxepin, imipramine, and trimipramine) or secondary amine (desipramine and nortriptyline).

Tertiary amines are generally more potent at blocking serotonin reuptake, whereas secondary amines are more potent at blocking norepinephrine reuptake. Secondary amines are better tolerated and associated with fewer anticholinergic side effects.

The CYP2C19 enzyme metabolizes tertiary amines into the active secondary amines, such as desipramine (the active metabolite of imipramine) and nortriptyline (the active metabolite of amitriptyline). Both tertiary and secondary amines are metabolized by CYP2D6 into less active metabolites. The effectiveness and tolerability of tricyclics are, therefore, affected by CYP2D6 metabolism and partially by CYP2C19 metabolism.

## Drug: Amitriptyline

Amitriptyline is used to relieve the symptoms of depression, with endogenous depression being more likely to respond to treatment than other depressive states (namely, reactive depression) (7). Off-label uses of amitriptyline include migraine prevention, and the treatment of neuropathic pain, fibromyalgia, irritable bowel syndrome, and enuresis (bedwetting) (8, 9, 10). It is also recommended for preventative management of tension-type headaches (11) and has been investigated in management of other types of pain and neuropathy as well as insomnia (9, 12, 13, 14, 15). It should be noted that these off-label uses often utilize lower doses than the primary indication of depression management.

Amitriptyline blocks the uptake of both serotonin and norepinephrine, but more potently blocks the reuptake of serotonin. Amitriptyline also has strong affinities for histamine (H1), alpha-1 adrenergic, and muscarinic (M1) receptors, which account for its side effects, including sedation, weight gain, blurred vision, dry mouth, and constipation. The intensity of these side effects tends to be greater for amitriptyline compared to other tricyclics (16). The frequency of side effects was noted to be particularly high with amitriptyline and topiramate as compared to other medications used for migraine prevention (17).

Amitriptyline is metabolized by CYP2C19 to the active metabolite, nortriptyline, which is also a tricyclic antidepressant that is approximately twice as potent as other TCAs. In contrast to amitriptyline, nortriptyline blocks the reuptake of norepinephrine more potently than serotonin (16). Because both the parent drug (amitriptyline) and the CYP2C19 metabolite (nortriptyline) are pharmacologically active compounds, the plasma levels of both drugs should be monitored as “active moiety” concentration (the sum concentration of amitriptyline and nortriptyline) (18). The active moiety plasma levels may correlate with an individual’s response to amitriptyline therapy (19). Both amitriptyline and nortriptyline are metabolized by CYP2D6 to inactive compounds (20).

The optimal therapeutic range for amitriptyline has been well-defined (21). Most individuals display an optimal response to amitriptyline when combined serum levels of amitriptyline and nortriptyline are between 80 and 200 ng/ml. Higher levels are associated with an increased risk of adverse events. At levels greater than 300 ng/ml, cardiac toxicity occurs. This is characterized by ECG changes (widening of QRS), which may lead to potentially fatal ventricular tachycardia. In some individuals, cardiac toxicity may occur at lower concentrations or even when they are within the recommended therapeutic range (22, 23). Nortriptyline is metabolized by CYP2D6 to hydroxyl metabolites, which have been associated with cardiac toxicity. Safe levels of hydroxyl metabolites have not yet been defined (18). Amitriptyline and other TCAs also cause decreased cardiac contractility and hypotension (24) and have been associated with very rare cases of cardiogenic shock and dilated cardiomyopathy (25). Historically, amitriptyline has been thought to be among the more toxic tricyclics in the context of medication overdose, though some analyses suggest that nearly all TCAs pose the same potential fatality risk in an overdose (26). In addition to changes in cardiac rhythm, amitriptyline therapy has also been associated with unhealthy lipid profiles, with higher doses corresponding to more severe abnormalities (27).

Additional serious side effects of amitriptyline therapy include worsening of depression, emergence of suicidal ideation, or both; pooled analyses indicate that individuals aged 18-25 were more likely to experience suicidality compared with adults 25 and older (1). Symptoms of anxiety, agitation, panic attacks, insomnia, hostility, impulsivity, akathisia, mania and hypomania have been observed in individuals treated with antidepressants and should be reported immediately to the health care provider (1). Individuals with angle-closure glaucoma may experience an angle closure attack in response to normal amitriptyline doses because of the anticholinergic effects. Caution and close supervision are recommended when amitriptyline is administered to individuals with a history of seizures (TCAs lower the seizure threshold) or hyperthyroidism (as a secondary effect). (1)

There is no evidence from clinical use that elderly individuals experience reduced efficacy with amitriptyline relative to younger adults, though dosing should be initiated at lower end of the normal range—50 mg total per day versus the adult recommended initial dosage of 75 mg per day (1). Individuals in this population are more likely to have decreased hepatic function, concomitant disease, or multiple medications that may alter drug metabolism. These individuals should also be closely monitored for anticholinergic side effects. A meta-analysis also reported that tricyclic use in older adults was not consistently associated with relief from chronic pain of various types and that risks of side effects were greater than the placebo or comparator medication (28).

The FDA drug label does not recommend amitriptyline for individuals under 12 years of age (1). However, one study of amitriptyline for enuresis used doses of 25 mg for children 6-10 years old and 50 mg for children 10-14 years of age (29) and a Cochrane review reports that tricyclics imipramine and amitriptyline were more effective at controlling pediatric nocturnal enuresis than placebo (30). However, this review also notes that efficacy is not sustained at the end of tricyclic therapy and there are uncertainties regarding potentially serious adverse effects of tricyclic medications in pediatric individuals (30).

Amitriptyline can cross the placenta and case reports have associated maternal amitriptyline use during pregnancy with adverse effects in the child, including limb deformities, developmental delay and CNS effects (1). Antidepressant use during the first trimester of pregnancy has also been associated with increased risk of preterm birth (31), exposure during second or third trimester may increase risk of adverse fetal outcomes (32). Maternal depression (with or without antidepressant therapy) is associated with increased risk for preterm birth and low APGAR scores (33). Amitriptyline during pregnancy is recommended only if the potential benefit to the mother justifies the potential risk to the child (1). Evidence-based clinical practice guidelines for prevention, screening, and treatment of peripartum depression strongly recommend the use of antidepressants after careful consideration of the individual risk-benefit ratio and further caution against discontinuation of antidepressant therapy during pregnancy due to the risk of major relapse (34). The FDA approved label states that there is a potential for serious adverse reactions in nursing infants with maternal amitriptyline use; the recommended actions are either to discontinue breast feeding or amitriptyline while considering the medical needs of the mother (1). Data indicates that the amount of amitriptyline and nortriptyline secreted in breastmilk represent an infant dosage of only 1.8% the maternal weight-adjusted dose (35). Rarely, sedation in a neonate has been observed in association with maternal amitriptyline use, though with infants over 2 months of age it is not expected to cause adverse events (35) . While one safety scoring system (36) reports amitriptyline use to be possible with caution during breastfeeding, other agents such as nortriptyline, paroxetine or sertraline may be preferred when larger doses are required or the infant is preterm or newborn (35).

Individuals who are carriers of certain variants in CYP2D6 or CYP2C19, or both may have drug levels that are outside the therapeutic range after treated with standard doses of amitriptyline. As a result, they may have an increased risk of toxicity (if the level of amitriptyline and its active metabolites are too high) or treatment failure (if drug levels are too low).

## Gene: CYP2D6

The cytochrome P450 superfamily (CYP450) is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are highly polymorphic and can result in decreased, absent, or increased enzyme activity. One prominent member, CYP2D6, is responsible for the metabolizing many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

The CYP2D6 gene is highly polymorphic, with over 170 star (*) alleles described and cataloged by the Pharmacogene Variation (PharmVar) Consortium (37, 38) Each defined allele is associated with either normal, increased, decreased, or absent enzyme function; however, many of the rare alleles remain uncharacterized and have unknown function (Table 5) (37, 38). PharmVar star (*) alleles are defined by the germline variants detected on a single chromosome and therefore represent independent haplotypes.

The combination of CYP2D6 haplotypes (or alleles) that an individual has is used to determine their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele is assigned an activity score from 0 to 1, which in turn is then used to assign a phenotype (for example, CYP2D6 PM). However, the activity score system is not standardized across all clinical laboratories or CYP2D6 genotyping platforms, leading to variability among results.

To promote harmonization, the CPIC and DPWG standardized their CYP2D6 genotype-to-phenotype methods in October 2019, creating a consensus activity scoring guideline. The CYP2D6 phenotype is predicted from the diplotype activity score, which is defined by the sum of the allele score values and typically ranges from 0–3.0: (39)

- An ultrarapid metabolizer (UM) has an activity score greater than 2.25
- A normal metabolizer phenotype (NM) has an activity score of 1.25–2.25
- An intermediate metabolizer (IM) has an activity score of >0–<1.25
- A poor metabolizer (PM) has an activity score of 0

Table 5.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *27, *33 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6). Activity scores from (39)

The CYP2D6*1 allele is considered the ‘normal’ wild-type allele, assigned when no variants are detected, and is associated with normal enzyme activity and the NM phenotype. The CYP2D6*2, *27, and *33 alleles are also annotated as having normal activity consistent with the *1 allele.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, and *6) (40, 41, 42, 43) or an enzyme with decreased activity (for example, *10, *17, and *41) (37, 44) (Table 5). There are significant interethnic differences in the frequency of these alleles. For example, *3, *4, *6, and *41 are more common in individuals of European ancestry, *17 is more common in African ancestry, and *10 is more common in Asian ancestry. (45)

Larger structural variants at the CYP2D6 locus have also been described, including gene duplications, deletions, tandem alleles, gene hybrids (namely, CYP2D6-CYP2D7), and gene conversions. As expected, deletions result in a no-function allele (for example, the *5 allele is a deletion). Duplications have been reported for alleles with normal function and decreased function. In cases of allele duplications, the activity scores for the full complement of CYP2D6 alleles are summed to determine the predicted metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (46).

The CYP2D6*2, *3, *4, *5, *6, *9, *10, *17, *29, *41 alleles and gene duplications or multiplications are the ‘Tier 1’ variants recommended by the Association for Molecular Pathology (AMP) for inclusion in CYP2D6 clinical genotyping assays .The AMP further recommends that testing laboratories consider *7, *8, *12, *14, *15, *21, *31, *40, *42, *49, *56, *59 alleles and CYP2D6-CYP2D7 hybrid genes as optional ‘Tier 2’ variants. These variants have all been shown to have decreased or no function but have either a low minor allele frequency or are technically more challenging to characterize (namely, the hybrid alleles). (47)

The frequency of the CYP2D6 star (*) alleles with altered function varies across global populations, resulting in different frequencies of the resulting metabolizer phenotype. Given CYP2D6’s role in the metabolism of many drugs, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency of normal-function star alleles, leading to a high proportion of the NM individuals. However, reduced-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, leading to a higher proportion of IM phenotype individuals in this ancestral group. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, which can correlate with lower metabolizer scores in these individuals. The frequency of UM is notably high in northern Africa, particularly in Algeria, mestizo Columbian population, the Druze ancestry group from the Middle East, and non-Austronesian Melanesian populations (48, 49). Given the distribution of duplicated, functional CYP2D6 alleles, some have proposed that a gene duplication event arose in populations based in the region of Saudi Arabia-Ethiopia, then spread through migration along the Mediterranean, resulting in a higher frequency of UM phenotype in the ancestral populations from these regions (50, 51). More information on allele and phenotype frequencies is available in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Other clinical factors and variables can influence CYP2D6 enzyme activity and, consequently, the metabolizer phenotype of any individual. The administration of an interacting medication can lead to a phenomenon called phenoconversion, wherein an individual with one metabolizer genotype exhibits the enzymatic activity of a different metabolizer group (higher or lower, depending on the medications).

The enzymatic activity of CYP2D6 can be inhibited or reduced by medications, including strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, as well as moderate inhibitors like duloxetine (52, 53, 54). This can potentially result in NMs or IMs to respond to medications as if they were PMs, depending on the strength of the enzyme inhibition. Strong inhibitors can completely inhibit CYP2D6 activity, while moderate inhibitors can reduce activity by 50%. Consequently, co-medication with multiple CYP2D6 strong or moderate inhibitors may result in reduced metabolism of drug substrates, as has been observed in psychiatric pharmacotherapy (55, 56). In contrast, discontinuing a concomitant CYP2D6 inhibitor can restore the individual's CYP2D6 activity to their genetically predicted phenotype baseline. Integration of CYP2D6 phenoconversion into clinical practice is highly relevant (57), but requires relevant professional expertise to incorporate all factors into clinical decision making. As such, EHR informatic tools have been developed to support clinicians in this process (58)

## Gene: CYP2C19

The CYP2C19 enzyme contributes to the metabolism of a range of clinically important drugs, including antidepressants, benzodiazepines, voriconazole, some proton pump inhibitors, and the antiplatelet agent, clopidogrel (59).

The CYP2C19 gene is highly polymorphic, with over 35 variant star (*) alleles cataloged by the PharmVar (https://www.pharmvar.org/gene/CYP2C19) Consortium. The CYP2C19*1 is considered the normal allele and is categorized with normal enzyme activity and the NM phenotype. Notably, the CYP2C19*1 haplotype has been determined to include a single nucleotide polymorphism in the coding region (rs3758581); however, the frequency of the variant nucleotide (G) is nearly 94% globally, and this missense variant does not alter protein function (60, 61, 62). The CYP2C19*38 is defined by the reference sequence with no variants and is also classified as normal function (62, 63).

The CYP2C19*17 allele is associated with increased enzyme activity and, depending on the number of alleles present, is associated with the “rapid” (RM) (one *17 allele) or “ultrarapid” (UM) (*17/*17 diplotype) metabolizer phenotype. Non-functional alleles include CYP2C19*2 and *3. The CYP2C19 IMs have one copy of an allele that encodes a non-functional enzyme (for example, *1/*2), whereas PMs have 2 non-functional alleles (for example, *2/*2, *2/*3) (Table 6). Individuals with one normal function allele and one decreased function allele are classified as having a “likely IM” phenotype (64).

Table 6.

Activity Status of Selected CYP2C19 Alleles

Allele type | Alleles
Increased function | CYP2C19*17
Normal function | CYP2C19*1 CYP2C19*38
Decreased function^ | CYP2C19*9 CYP2C19*10
No function | CYP2C19*2 CYP2C19*3 CYP2C19*4 CYP2C19*5 CYP2C19*6 CYP2C19*7 CYP2C19*8 CYP2C19*35
Uncertain function | CYP2C19*12

This table is adapted from (65).

^ Note: the evidence supporting the activity status of decreased-function alleles is limited.

Approximately 2% of Caucasians, 4% of African Americans, 14% of Chinese, and 57% of Oceanians are CYP2C19 PM, while up to 45% of individuals are CYP2C19 IM (66).

The most common no-function variant is CYP2C19*2, which is defined by 3 single nucleotide variants: NM_000769.4:c.332-23A>G, NM_000769.1:c.681G>A, and NM_000769.4:c.991A>G. These variants result in aberrant mRNA splicing and produce a truncated, non-functioning protein. The CYP2C19*2 allele frequencies are between 12–18% in individuals of European, American, or African ancestry; 25–35% in Asians, Native Hawaiians, and Pacific Islanders; and up to 60% in Oceanian populations (66, 67).

For CYP2C19, another commonly tested no-function variant is CYP2C19*3, which contains a c.636G>A variant in exon 4 that causes a premature stop codon. The CYP2C19*3 allele frequencies are ~2–9% in Asian populations, but are rare in other ancestral populations (67). Other non-functional variants, such as CYP2C19*4–*8, occur in less than 1% of the general population (68).

The frequency of the CYP2C19*17 allele is approximately 22% in individuals of European ancestry, 8% in individuals from the Americas, 0.5–5.7% in Asian, Native Hawaiian, and Pacific Islander populations, 17% in African populations, and 20% in African American and Afro-Caribbean populations (66 , 67).

The CYP2C19*2, *3, and *17 alleles are the ‘Tier 1’ alleles recommended by the Association for Molecular Pathology (AMP) for inclusion in CYP2C19 clinical genotyping assays (69). The AMP further recommends that testing laboratories consider *4, *5, *6, *7, *8, *9, *10, and *35 alleles as optional ‘Tier 2’ alleles. These alleles have all been shown to have decreased or no function but have either a low minor allele frequency, limited data characterizing the impact on enzyme function, or lack reference materials. Among the ‘Tier 2’ alleles, the CYP2C19*35 allele is the most common, with a frequency of 9% in African populations (69).

Pharmacologic Conversion of CYP2C19 Phenotype

Many medicines are metabolized by the CYP2C19 enzyme, and the enzyme’s activity level can be altered by the administration of medications or supplements. Significant changes in effective enzyme activity due to co-medication or non-genetic factors is called phenoconversion. Increased enzymatic activity can result from the induction of CYP2C19, for example, this effect can occur with medications like rifampin, phenytoin, efavirenz, or apalutamide. (70) St. John’s wort and smoking may also increase CYP enzyme activity (71). Inhibitors of CYP2C19, such as such as omeprazole, fluoxetine, fluvoxamine, fluconazole, or voriconazole, may also impact the target drug metabolism of the target drug (70, 72). Cannabidiol (CBD) can also inhibit CYP2C19 and increase plasma concentrations of other CYP2C19 substrates (73, 74). It should be noted that CBD is available in both prescription form and unregulated, over-the-counter supplements, which may lead to unanticipated phenoconversion (75). The frequency of phenoconversion for CYP2C19 was observed to be much lower than CYP2D6 in a population being treated for psychiatric conditions (76).

Other Genes of Interest: SLC22A1

The organic cation transporter 1 (OCT1) protein is encoded by SLC22A1. This transport protein has a broad substrate profile and is expressed in hepatocytes and has been investigated as a potential contributor to pharmacokinetics of various medications. (77) Amitriptyline was observed to cause in vitro inhibition of OCT1 and while healthy study participants showed no change in pharmacokinetics in a single dose study, there was a correlation between reduced OCT1 activity levels and increased plasma amitriptyline in a cohort being treated for depression (78).

## Linking Gene Variation with Treatment Response

Genetic variation in CYP2D6 and CYP2C19 have been associated with altered drug levels of amitriptyline among adult individuals (79).

CYP2D6

Individuals that are CYP2D6 IM have a slightly higher exposure than NM (79). Plasma concentrations of amitriptyline and nortriptyline showed an increase with decreased CYP2D6 activity and a longer plasma half-life with lower amitriptyline clearance in a study of healthy individuals (78). While CYP2D6 UM genotype individuals are rare, there are observations of even further decreased plasma concentration in these individuals compared to other metabolizer groups, though this difference in pharmacokinetics did not correspond to changes in clinical response (57).

Another small study from the Faroe Islands found that PMs (by phenotype, confirmed to be CYP2D6*4/*4) had much lower levels of hydroxylated amitriptyline and nortriptyline compared with NM individuals. However, only 1 of 5 PMs had amitriptyline and nortriptyline total plasma concentration above the recommended range, possibly attributed to lower doses that were clinically indicated in this study cohort. There was no indication that PMs were administered lower doses than NMs. Notably, the PM frequency in this geographically isolated population is reported to be 15%. (80)

There is evidence supporting phenoconversion of CYP2D6 to IM or PM can impact amitriptyline exposure in clinical use, leading one study’s authors to recommend dose reduction for individuals who are likely to be PMs after accounting for phenoconversion (57).

CYP2C19

Individuals who are CYP2C19 poor metabolizers have a reduced rate of metabolism of amitriptyline compared with normal metabolizers. As a result, standard doses of amitriptyline lead to higher plasma levels of amitriptyline, lower levels of nortriptyline, and may increase the risk of side effects (81, 82, 83, 84). Individuals with predicted PM phenotype were more likely than NM to experience treatment emergent mania with amitriptyline therapy for bipolar depression (85).

Individuals who are CYP2C19 ultrarapid metabolizers may be at an increased risk of treatment failure, metabolite-based adverse effects, or both. One study found that CYP2C19 UM or RM had lower serum concentration (amitriptyline plus nortriptyline) to dose ratios versus NM (76). Another study reported higher CYP2C19 activity correlated with higher nortriptyline exposure (78). Being a carrier of the increased activity allele CYP2C19*17 is not associated with an increased level of the sum of amitriptyline plus nortriptyline levels, but the ratio is altered and higher levels of nortriptyline have been reported, which may be linked to increased side effects (18, 81).

It should be noted that a systematic review failed to find consistent replication of association between specific genes (including CYP2D6, CYP2C19, ABCB1, and BDNF among others) and antidepressant response or tolerability in children and young adults, possibly attributable to the lack of power in the reviewed studies (86).

## Genetic Testing

Clinical molecular tests are available for CYP2D6 and CYP2C19 genotyping from both academic and commercial laboratories. In addition, the NIH’s Genetic Testing Registry (GTR) provides a list of tests for amitriptyline response (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN176769%5BDISCUI), and the CYP2D6 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5Bgeneid%5D) and CYP2C19 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1557%5Bgeneid%5D) genes.

The available CYP2D6 tests include targeted single-gene tests as well as multi-gene panels. The AMP has recommended variant CYP2D6 alleles to be included in clinical genotyping assays (87), including a minimum panel of ‘Tier 1’ variant alleles (*2, *3, *4, *5, *6, *9, *10, *17, *29, *41 and copy number interrogation) (47). Guidance on recommended alleles for clinical testing of CYP2C19 is also available from the AMP, with CYP2C19*2, *3 and *17 as ‘Tier 1’ alleles (69).

Usually, an individual’s result is reported as a diplotype, such as CYP2C19 *1/*1 or CYP2D6 *1/*1 and may also include an interpretation of the individual’s predicted metabolizer phenotype (ultrarapid, rapid, normal, intermediate, or poor). It is important to note that copy number testing is critical when interpreting CYP2D6 results (88). When individuals have more than 2 copies of CYP2D6, the allele copies are denoted by an “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6*1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use the notation of DUP to indicate an increase in copy number; however, the report may not always specify the number of duplications or the allele duplicated due to technical limitations.

The test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be confirmed by checking the diplotype and calculating the CYP2D6 activity score, as described in the “CYP2D6 Alleles” section above. When a test report does not provide a predicted metabolizer phenotype, resources such as PharmVar (https://www.pharmgkb.org/page/pharmvar) are available to assist with predicting the functional impact of identified variants.

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in real-world clinical settings (89, 90, 91). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, where gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (92).

## The CYP2D6 and CYP2C19 Gene Interactions with Medications Used for Additional Indications

The CYP family of enzymes is involved in the metabolism of many substances and CYP2D6 especially has been implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

- Antipsychotics—for example, aripiprazole, risperidone, thioridazine and—to a lesser extent—clozapine is metabolized by CYP2D6. According to the FDA, aripiprazole dosage should be reduced for PMs and thioridazine is contraindicated for individuals who are known to have reduced CYP2D6 activity due to increased risk of potentially fatal side effects. The UMs may have a decreased plasma concentration of risperidone, per DPWG recommendations.
- Cardiovascular diseases—for example, metoprolol, carvedilol, and propafenone are used to manage arrhythmias or heart failure and changes in CYP2D6 activity can impact the levels of these medications.
- Serotonin and norepinephrine reuptake inhibitors—for example atomoxetine and venlafaxine may have reduced efficacy in UMs at standard doses while PMs are at risk of elevated plasma concentrations for both medications. The Dutch Pharmacogenetics Working Group advises against the use of venlafaxine in CYP2D6 PMs and IMs.
- Anticancer medications—for example, tamoxifen is activated by CYP2D6, and IMs or PMs may have reduced benefit from tamoxifen therapy.
- Pain management—for example, codeine and tramadol are pro-drugs that require activation by CYP2D6 to achieve the desired analgesic effect. Oxycodone is also metabolized by CYP2D6, but there are no actionable prescribing recommendations for this gene-drug pair.
- Antimalarial medications—for example, primaquine must be metabolized by CYP2D6 to form the hydroxylated active metabolite that targets the parasite.
- Various therapies for genetic disorders—for example eliglustat used in the treatment of Gaucher disease and deutetrabenazine and valbenazine used in the treatment of Huntington disease and tardive dyskinesia may require dose adjustments based on genotype.

It is important to note that CYP2D6 is the most common biomarker in drug responses for FDA drug labels; the list provided here is by no means exhaustive. Additional information on gene-drug interactions for CYP2D6 are available from ClinPGx (https://www.clinpgx.org/gene/PA128), CPIC (https://www.clinpgx.org/cpic/pairs) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

Other medications affected by CYP2C19 genetic variation may be used to treat:

- Acute coronary syndrome –– individuals who are CYP2C19 poor metabolizers and undergoing percutaneous coronary intervention have an increased risk of cardiovascular events if they are treated with the antiplatelet drug clopidogrel (a pro-drug that is activated by CYP2C19-mediated metabolism).
- Gastrointestinal ulcers, gastroesophageal reflux, erosive esophagitis, and Helicobacter pylori infection—PPIs like omeprazole, esomeprazole (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/esomeprazole/), and others may have reduced metabolism in CYP2C19 IMs and PMs and thus these individuals have higher exposure to these medications, which imparts risk of adverse events. Conversely, CYP2C19*17 confers increased activity and thus a more rapid clearance of PPIs and potential for treatment failure in UMs.
- Antifungal treatment—voriconazole (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/voriconazole/) is metabolized by CYP2C19 and UMs may have delayed target blood concentrations due to rapid clearance; PMs may experience high exposure and have a risk of adverse events.
- Depression, anxiety disorders, obsessive-compulsive disorder, or migraine prophylaxis—both selective serotonin reuptake inhibitors (SSRIs, such as citalopram, escitalopram, and sertraline) and tricyclic antidepressants (TCAs, such as the tertiary amines clomipramine, doxepin, imipramine (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/imipramine/), and trimipramine) can be metabolized by CYP2C19. When administering SSRIs, UMs may experience treatment failure due to high clearance while PMs may require dose reduction. For the tertiary amine TCAs, UMs may experience altered responses or side effects due to rapid conversion to secondary amines while PMs are at risk of suboptimal responses and may require a lower dose. Diazepam (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/diazepam/) is also partially metabolized by CYP2C19 and altered enzyme function may contribute to altered clearance of this medication.
- Epilepsy or seizures—brivaracetam (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/brivaracetam/), used for partial-onset (focal) epilepsy, is partially metabolized by CYP2C19 and PMs may require lower doses to avoid adverse effects due to reduced clearance of this medication. Clobazam (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/clobazam/) is used to manage seizures in a variety of conditions and CYP2C19 PMs may experience higher exposure to norclobazam, putting them at higher risk for adverse effects. Lacosamide (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/lacosamide/) is also metabolized by CYP2C19, though there is no indication that PMs require altered dosing or management.
- Musculoskeletal pain—carisoprodol (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/carisoprodol/), a centrally acting muscle relaxant, is metabolized by CYP2C19 and PMs may be at a higher risk of carisoprodol toxicity.
- Hypoactive sexual desire disorder—flibanserin (https://www.ncbi.nlm.nih.gov/books/n/gtrbook/flibanserin/) is metabolized, in part, by CYP2C19 and PMs have a higher exposure to this medication, resulting in an elevated risk of hypotension, syncope, and CNS depression.

Additional information on gene-drug interactions for CYP2C19 are available from ClinPGx (https://www.clinpgx.org/gene/PA124/), CPIC (https://www.clinpgx.org/cpic/pairs) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2C19”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2024 Statement from the US Food and Drug Administration (FDA)

The biochemical activity of the drug metabolizing isozyme cytochrome P450 2D6 (debrisoquin hydroxylase) is reduced in a subset of the Caucasian population (about 7 to 10% of Caucasians are so called “poor metabolizers”); reliable estimates of the prevalence of reduced P450 2D6 isozyme activity among Asian, African and other populations are not yet available. Poor metabolizers have higher than expected plasma concentrations of tricyclic antidepressants (TCAs) when given usual doses. Depending on the fraction of drug metabolized by P450 2D6, the increase in plasma concentration may be small, or quite large (8 fold increase in plasma AUC of the TCA).

In addition, certain drugs inhibit the activity of this isozyme and make normal metabolizers resemble poor metabolizers. An individual who is stable on a given dose of TCA may become abruptly toxic when given one of these inhibiting drugs as concomitant therapy. The drugs that inhibit cytochrome P450 2D6 include some that are not metabolized by the enzyme (quinidine; cimetidine) and many that are substrates for P450 2D6 (many other antidepressants, phenothiazines, and the Type 1C antiarrhythmics propafenone and flecainide). While all the selective serotonin reuptake inhibitors (SSRIs), e.g., fluoxetine, sertraline, and paroxetine, inhibit P450 2D6, they may vary in the extent of inhibition. The extent to which SSRI-TCA interactions may pose clinical problems will depend on the degree of inhibition and the pharmacokinetics of the SSRI involved. Nevertheless, caution is indicated in the coadministration of TCAs with any of the SSRIs and also in switching from one class to the other. Of particular importance, sufficient time must elapse before initiating TCA treatment in a patient being withdrawn from fluoxetine, given the long half-life of the parent and active metabolite (at least 5 weeks may be necessary).

Concomitant use of tricyclic antidepressants with drugs that can inhibit cytochrome P450 2D6 may require lower doses than usually prescribed for either the tricyclic antidepressant or the other drug. Furthermore, whenever one of these other drugs is withdrawn from co-therapy, an increased dose of tricyclic antidepressant may be required. It is desirable to monitor TCA plasma levels whenever a TCA is going to be coadministered with another drug known to be an inhibitor of P450 2D6.

FDA Pharmacogenetics Associations for which the data demonstration a potential impact on pharmacokinetic properties only

Drug | Gene | Affected Subgroups | Description of Gene-Drug interaction
Amitriptyline | CYP2D6 | Ultrarapid, intermediate, or poor metabolizers | May alter systemic concentrations

Please review the complete therapeutic recommendations that are located here: (1, 5).

### 2023 Summary of recommendations from the Pharmacogenetics Working Group of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

CYP2D6 UM: amitriptyline

The risk of ineffectiveness is increased and the risk of cardiotoxic side effects may be increased. The gene variation leads to increased conversion of amitriptyline and the active metabolite nortriptyline to less active and inactive metabolites.

- increase the dose to 1.6 times the normal dose, monitor the effect and side effects or the plasma concentrations and be alert to increased plasma concentrations of the cardiotoxic Z-10-hydroxy metabolites

Plasma concentrations of Z-hydroxy nortriptyline or Z-hydroxy amitriptyline higher than 40 ng/mL are considered toxic.

- if a dose increase is not desirable due to the cardiotoxic hydroxy metabolite: avoid amitriptyline. Anti-depressants that are not metabolised by CYP2D6, or to a lesser extent, include citalopram and sertraline.

CYP2D6 IM: amitriptyline

The risk of side effects is increased, because the gene variation leads to higher plasma concentrations of the active metabolite nortriptyline and to a lesser extent of amitriptyline.

- use 75% of the normal dose and monitor the efficacy and side effects or the plasma concentrations of amitriptyline and nortriptyline to adjust the maintenance dose

CYP2D6 PM: amitriptyline

In theory, risk of side effects is increased, because the genetic variation results in higher plasma concentrations of the active metabolite nortriptyline and to a lesser extent of amitriptyline.

- use 60% of the normal dose and monitor the effect and side effects or the plasma concentrations of amitriptyline and nortriptyline to adjust the maintenance dose

CYP2C19 IM: amitriptyline

NO action is required for this gene-drug interaction.

The gene variation has an effect on the exposure to amitriptyline, but not on the exposure to amitriptyline + the active metabolite nortriptyline, which determines the effect and side effects.

CYP2C19 PM: amitriptyline

NO action is required for this gene-drug interaction.

The gene variation has an effect on the exposure to amitriptyline, but not on the exposure to amitriptyline + the active metabolite nortriptyline, which determines the effect and side effects.

CYP2C19 UM: amitriptyline

NO action is required for this gene-drug interaction.

The gene variation decreases the exposure to amitriptyline and increases the exposure to the active metabolite nortriptyline, but there is no evidence to indicate that this results in an increase in side effects or a decrease in efficacy. A higher dose is required to achieve the therapeutic range of amitriptyline+nortriptyline, but the therapeutic range of nortriptyline is achieved at the lower dose.

Please review the complete therapeutic recommendations and their most recent updates that are located here: (2).

### 2016 Statement from the Clinical Pharmacogenetics Implementation Consortium (CPIC)

CYP2D6 dosing recommendations.

[…]. The recommended starting dose of amitriptyline or nortriptyline does not need adjustment for those with genotypes predictive of CYP2D6 normal metabolism. A 25% reduction of the recommended dose may be considered for CYP2D6 intermediate metabolizers. The strength of this recommendation is classified as “moderate” because patients with a CYP2D6 activity score of 1.0 are inconsistently categorized as intermediate or normal metabolizers in the literature, making these studies difficult to evaluate.

In the October 2019 update from CPIC: “The recommendation for CYP2D6 IM (reduce starting dose by 25%) should be considered for CYP2D6 AS of 1 (strength of recommendation: optional).”

CYP2D6 ultrarapid metabolizers have a higher probability of failing amitriptyline or nortriptyline pharmacotherapy due to subtherapeutic plasma concentrations, and alternate agents are preferred. There are documented cases of CYP2D6 ultrarapid metabolizers receiving large doses of nortriptyline in order to achieve therapeutic concentrations. However, very high plasma concentrations of the nortriptyline hydroxy-metabolite were present, which may increase the risk for cardiotoxicity. If a tricyclic is warranted, there are insufficient data in the literature to calculate a starting dose for a patient with CYP2D6 ultrarapid metabolizer status, and therapeutic drug monitoring is strongly recommended.

Adverse effects are more likely in CYP2D6 poor metabolizers due to elevated tricyclic plasma concentrations; therefore, alternate agents are preferred. If a tricyclic is warranted, consider a 50% reduction of the usual dose, and therapeutic drug monitoring is strongly recommended.

CYP2C19 dosing recommendations.

[…]. The usual starting dose of amitriptyline may be used in CYP2C19 normal and intermediate metabolizers. Although CYP2C19 intermediate metabolizers would be expected to have a modest increase in the ratio of amitriptyline to nortriptyline plasma concentrations, the evidence does not indicate that CYP2C19 intermediate metabolizers should receive an alternate dose.

Patients taking amitriptyline who are CYP2C19 rapid or ultrarapid metabolizers may be at risk for having low plasma concentrations and an imbalance between parent drug and metabolites causing treatment failure and/or adverse events. Although the CYP2C19*17 allele did not alter the sum of amitriptyline plus nortriptyline plasma concentrations, it was associated with higher nortriptyline plasma concentrations, possibly increasing the risk of adverse events. For patients taking amitriptyline, extrapolated pharmacokinetic data suggest that CYP2C19 rapid or ultrarapid metabolizers may need a dose increase. Due to the need for further studies investigating the clinical importance of CYP2C19*17 regarding tricyclic metabolism and the possibility of altered concentrations, we recommend to consider an alternative tricyclic or other drug not affected by CYP2C19. This recommendation is classified as optional due to limited available data. If amitriptyline is administered to a CYP2C19 rapid or ultrarapid metabolizer, therapeutic drug monitoring is recommended.

CYP2C19 poor metabolizers are expected to have a greater ratio of amitriptyline to nortriptyline plasma concentrations. The elevated amitriptyline plasma concentrations may increase the chance of a patient experiencing side effects. Use an alternative agent not metabolized by CYP2C19 (e.g., nortriptyline and desipramine) or consider a 50% reduction of the usual amitriptyline starting dose along with therapeutic drug monitoring.

Please review the complete therapeutic recommendations that are located here: (4, 6).

## Nomenclature

Nomenclature for selected CYP2D6 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2 ^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2 ^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3 ^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4 ^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5 ^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7 ^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8 ^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9 ^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10 ^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10 ^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17 ^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17 ^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17 ^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12 ^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14 ^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15 ^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21 ^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29 ^[1]^ | 1660G>A+1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29 ^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29 ^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29 ^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31 ^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36 ^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36 ^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36 ^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36 ^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36 ^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36 ^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36 ^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36 ^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40 ^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40 ^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40 ^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41 ^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41 ^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41 ^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49 ^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49 ^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56 ^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59 ^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59 ^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59 ^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (87)

^[2]^ AMP Tier 2 allele, (87)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (93)

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (https://www.pharmvar.org/)) Consortium (63).

Nomenclature for Selected CYP2C19 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2C19*2 ^[1]^ | 681G>A | NM_000769.1:c.681G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16897/) | NP_000760.1:p.Pro227= | rs4244285 (https://www.ncbi.nlm.nih.gov/snp/rs4244285)
CYP2C19*2 ^[1]^ | 12662A>G | NM_000769.1:c.332-23A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633850/) | (Splicing defect) | rs12769205 (https://www.ncbi.nlm.nih.gov/snp/rs12769205)
CYP2C19*2 ^[1]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*3 ^[1]^ | 636G>A | NM_000769.1:c.636G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/16899/) | NP_000760.1:p.Trp212Ter | rs4986893 (https://www.ncbi.nlm.nih.gov/snp/4986893)
CYP2C19*3 ^[1]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*4 ^[2]^ | 1A>G | NM_000769.4:c.1A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/16900/) | NP_000760.1:p.Met1Val | rs28399504 (https://www.ncbi.nlm.nih.gov/snp/rs28399504)
CYP2C19*4 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*5 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*5 ^[2]^ | 90033C>T | NM_000769.4:c.1297C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16898) | NP_000760.1:p.Arg433Trp | rs56337013 (https://www.ncbi.nlm.nih.gov/snp/rs56337013)
CYP2C19*6 ^[2]^ | 12748G>A | NM_000769.4:c.395G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39350) | NP_000760.1:p.Arg132Gln | rs72552267 (https://www.ncbi.nlm.nih.gov/snp/rs72552267)
CYP2C19*6 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*7 ^[2]^ | 19294T>A | NM_000769.4:c.819+2T>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39348/) | (Splicing defect) | rs72558186 (https://www.ncbi.nlm.nih.gov/snp/rs72558186)
CYP2C19*7 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*8 ^[2]^ | 12711T>C | NM_000769.4:c.358T>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39351/) | NP_000760.1:p.Trp120Arg | rs41291556 (https://www.ncbi.nlm.nih.gov/snp/rs41291556)
CYP2C19*8 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*9 ^[2]^ | 12784G>A | NM_000769.1:c.431G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39352/) | NP_000760.1:p.Arg144His | rs17884712 (https://www.ncbi.nlm.nih.gov/snp/rs17884712)
CYP2C19*9 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*10 ^[2]^ | 19153C>T | NM_000769.4:c.680C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39353/) | NP_000760.1:p.Pro227Leu | rs6413438 (https://www.ncbi.nlm.nih.gov/snp/rs6413438)
CYP2C19*10 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*12 | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*12 | 90209A>C | NM_000769.4:c.1473A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/633853/) | NP_000760.1:p.Ter491Cys | rs55640102 (https://www.ncbi.nlm.nih.gov/snp/rs55640102)
CYP2C19*17 ^[1] [3]^ | -806C>T | NG_008384.3:g.4220C>T (NM_000769.2:c.-806C>T)^[3]^ | Not applicable—variant occurs in a non-coding region | rs12248560 (https://www.ncbi.nlm.nih.gov/snp/12248560)
CYP2C19*19 | 151A>G | NM_000769.4:c.151A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633933/) | NP_000760.1:p.Ser51Gly | rs1564657013 (https://www.ncbi.nlm.nih.gov/snp/rs1564657013)
CYP2C19*19 | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*35 ^[2]^ | 12662A>G | NM_000769.1:c.332-23A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/633850/) | (Splicing defect) | rs12769205 (https://www.ncbi.nlm.nih.gov/snp/rs12769205)
CYP2C19*35 ^[2]^ | 80161A>G | NM_000769.4:c.991A>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/39354/) | NP_000760.1:p.Ile331Val | rs3758581 (https://www.ncbi.nlm.nih.gov/snp/rs3758581)
CYP2C19*38 | | NM_000769.4 | NP_000760.1 | (none)

^[1]^ AMP Tier 1 allele (69)

^[2]^ AMP Tier 2 allele (69)

^[3]^ The CYP2C19*17 allele has increased expression due to an upstream, non-coding variant. The legacy HGVS expression for the change relative to the coding sequence is provided, but the correct RefSeq genomic sequence is provided as well.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (93)

Nomenclature for Cytochrome P450 enzymes is available from the PharmVar database (37) https://www.pharmvar.org/

## Acknowledgments

Version 1.0 (Published March 23, 2017)

The author would like to thank the following individuals for reviewing this summary: David Kisor, B.S., Pharm.D., Professor and Director of Pharmacogenomics Education, Pharmacogenomics Program, Manchester University, Indiana; Mohamed Nagy, Clinical Pharmacist, Head of the Personalised Medication Management Unit, Department of pharmaceutical Services, Children's Cancer Hospital, Egypt; Yolande Saab, Pharm.D., Ph.D., Associate Professor of Pharmacogenomics, School of Pharmacy, Lebanese American University, Lebanon; Stuart Scott, Assistant Professor of Genetics and Genomic Sciences, Icahn School of Medicine at Mount Sinai; Chakradhara Rao S Uppugunduri, Maître-assistant at the CANSEARCH Laboratory, University of Geneva, Switzerland; and Mandy van Rhenen, secretary of the Dutch Pharmacogenetics Working Group (DPWG), Centre for Information on Medicines, Royal Dutch Pharmacists Association (KNMP).

Version 2.0 (Published June 23, 2025)

The authors would like to acknowledge Maike Scherf-Clavel, Dr. rer. Nat., Department of Psychiatry, Psychosomatics and Psychotherapy, Center of Mental Health, University Hospital of Würzburg, Würzburg, Germany; Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherland; and James Walker, PharmD, MSPGx, Chief Executive Officer, PharmaGx Consultation, Wichita, Kansas, USA for their expert review of this summary.

## Version History

Version 1 of this summary was published on March 23, 2017 and is available here.

Version 2.0 of this summary was published on June 23, 2025. This chapter includes updated guidance from the Dutch Pharmacogenetics Working Group regarding CYP2D6 genotype-guided dosing of amitriptyline. Additionally, guidelines from the Association for Molecular Pathology for CYP2D6 and CYP2C19 alleles to be included in pharmacogenetic testing are included in this update.

A minor revision (v 2.1) was made on May 18, 2026 to update links to CPIC and ClinPGx (formerly PharmGKB) resources.

## References

1 AMITRIPTYLINE HYDROCHLORIDE tablet, film coated. Princeton, NJ, USA: Sandoz Inc; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=705a2bae-031d-4218-82fe-4346542c0baa.
2 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. Pharmacogenetic Recommendation Text (Version 2) [Cited September 2024]. Available from https://www.knmp.nl/dossiers/farmacogenetica.
3 CYP2D6: amitriptyline risk analysis [Cited 14 May 2025]. Available from https://www.g-standaard.nl/risicoanalyse/M0002571.pdf.
4 Kevin Hicks, J., K. Sangkuhl, J.J. Swen, V.L. Ellingrod, et al., Clinical Pharmacogenetics Implementation Consortium Guideline (CPIC(R)) for CYP2D6 and CYP2C19 Genotypes and Dosing of Tricyclic Antidepressants: 2016 Update. Clin Pharmacol Ther, 2016.
5 FDA, U. Table of Pharmacogenetic Associations. 2022 10/26/2022 [cited 2024; Available from: https://www.fda.gov/medical-devices/precision-medicine/table-pharmacogenetic-associations#section3.
6 CPIC. CPIC® Guideline for Tricyclic Antidepressants and CYP2D6 and CYP2C19. 2019 October 2019 14 May 2025]; Available from: https://cpicpgx.org/guidelines/guideline-for-tricyclic-antidepressants-and-cyp2d6-and-cyp2c19/.
7 AMITRIPTYLINE HYDROCHLORIDE- amitriptyline hydrochloride tablet, film coated. Durham, NC: Inc, A.H.; 2016. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=1e6d2c80-fbc8-444e-bdd3-6a91fe1b95bd.
8 Jones, E.A., F. Asaad, N. Patel, E. Jain, and A. Abd-Elsayed, Management of Fibromyalgia: An Update. Biomedicines, 2024. 12(6).38927473
9 Marchesini, M., G. Topi, C. Bonezzi, and L. Demartini, Amitriptyline-perphenazine therapy for persistent idiopathic facial pain: translational perspectives from a retrospective study. J Anesth Analg Crit Care, 2024. 4(1): p. 83.39695777
10 Iqbal, M., S. Hira, H. Saeed, S. Shahid, et al., Efficacy of Amitriptyline in Irritable Bowel Syndrome: A Systematic Review and Meta-analysis. J Neurogastroenterol Motil, 2025. 31(1): p. 28-37.39779201
11 Sico, J.J., N.M. Antonovich, J. Ballard-Hernandez, A.C. Buelt, et al., 2023 U.S. Department of Veterans Affairs and U.S. Department of Defense Clinical Practice Guideline for the Management of Headache. Ann Intern Med, 2024. 177(12): p. 1675-1694.39467289
12 Licata, G., E.V. Di Brizzi, V. Tancredi, M. Arisi, et al., Amitriptyline for the treatment of vulvodynia in patients with vulvar lichen sclerosus: a case series of 20 patients. Int J Dermatol, 2025.39757140
13 Chen, Y., L. Liu, X. Kong, J. Sun, et al., Clinical effects of combined use of carbamazepine and amitriptyline in the treatment of diabetic neuropathy with concurrent diabetic foot. Int J Neurosci, 2024: p. 1-7.38597593
14 Bakker, M., J.G. Hugtenburg, P.M. Bet, J.W.R. Twisk, et al., Effectiveness of low-dose amitriptyline and mirtazapine in patients with insomnia disorder with sleep maintenance problems: a randomised, double-blind, placebo-controlled trial in general practice (DREAMING). Br J Gen Pract, 2025.39814428
15 Klugherz, L.J., M.P. Mansukhani, and B.P. Kolla, Effects of Commonly Prescribed Medications on Sleep: A Review of the Literature. Mayo Clin Proc, 2025. 100(5): p. 856-867.40318905
16 UpToDate. Tricyclic and tetracyclic drugs: Pharmacology, administration, and side effects [Cited August 2, 2016]. Available from https://www.uptodate.com/contents/tricyclic-and-tetracyclic-drugs-pharmacology-administration-and-side-effects?source=machineLearning&search=tricyclic+antidepressants&selectedTitle=1~150&sectionRank=2&anchor=H31#references.
17 Naghdi, S., M. Underwood, A. Brown, M. Matharu, et al., Adverse and serious adverse events incidence of pharmacological interventions for managing chronic and episodic migraine in adults: a systematic review. BMJ Neurol Open, 2024. 6(1): p. e000616.38646505
18 Hicks, J.K., J.J. Swen, C.F. Thorn, K. Sangkuhl, et al., Clinical Pharmacogenetics Implementation Consortium guideline for CYP2D6 and CYP2C19 genotypes and dosing of tricyclic antidepressants. Clin Pharmacol Ther, 2013. 93(5): p. 402-8.23486447
19 Perry, P.J., C. Zeilmann, and S. Arndt, Tricyclic antidepressant concentrations in plasma: an estimate of their sensitivity and specificity as a predictor of response. J Clin Psychopharmacol, 1994. 14(4): p. 230-40.7962678
20 Aka, I., C.J. Bernal, R. Carroll, A. Maxwell-Horn, et al., Clinical Pharmacogenetics of Cytochrome P450-Associated Drugs in Children. J Pers Med, 2017. 7(4).29099060
21 Hiemke, C., P. Baumann, N. Bergemann, A. Conca, et al., AGNP consensus guidelines for therapeutic drug monitoring in psychiatry: update 2011. Pharmacopsychiatry, 2011. 44(6): p. 195-235.
22 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*41 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816584.
23 Ulrich, S. and J. Lauter, Comprehensive survey of the relationship between serum concentration and therapeutic effect of amitriptyline in depression. Clin Pharmacokinet, 2002. 41(11): p. 853-76.12190332
24 Nguyen, T.T., L.D. Le, T.T. Vu, A.T. Nguyen, et al., Resuscitation from Respiratory Arrest Due to Life-Threatening Ventricular Arrhythmias in a Patient with Amitriptyline Intoxication: An Old Problem in a New Era. Int Med Case Rep J, 2024. 17: p. 949-957.39554902
25 Kauffman, Z.S. and M. Demede, Dilated Cardiomyopathy, De Novo Heart Failure, and Cardiogenic Shock With End-Organ Failure in a Patient With No Cardiac History Following a Trial of Amitriptyline. Cureus, 2024. 16(8): p. e67374.39310625
26 Taylor, D., S. Poulou, and I. Clark, The cardiovascular safety of tricyclic antidepressants in overdose and in clinical use. Ther Adv Psychopharmacol, 2024. 14: p. 20451253241243297.38827015
27 Richards-Belle, A., I. Austin-Zimmerman, B. Wang, E. Zartaloudi, et al., Associations of antidepressants and antipsychotics with lipid parameters: Do CYP2C19/CYP2D6 genes play a role? A UK population-based study. J Psychopharmacol, 2023. 37(4): p. 396-407.36772859
28 Narayan, S.W., V. Naganathan, L. Vizza, M. Underwood, et al., Efficacy and safety of antidepressants for pain in older adults: A systematic review and meta-analysis. Br J Clin Pharmacol, 2024. 90(12): p. 3097-3118.39265130
29 Burke, J.R., Y. Mizusawa, A. Chan, and K.L. Webb, A comparison of amitriptyline, vasopressin and amitriptyline with vasopressin in nocturnal enuresis. Pediatr Nephrol, 1995. 9(4): p. 438-40.7577405
30 Caldwell, P.H., P. Sureshkumar, and W.C. Wong, Tricyclic and related drugs for nocturnal enuresis in children. Cochrane Database Syst Rev, 2016. 2016(1): p. CD002117.26789925
31 Sujan, A.C., M.E. Rickert, A.S. Oberg, P.D. Quinn, et al., Associations of Maternal Antidepressant Use During the First Trimester of Pregnancy With Preterm Birth, Small for Gestational Age, Autism Spectrum Disorder, and Attention-Deficit/Hyperactivity Disorder in Offspring. JAMA, 2017. 317(15): p. 1553-1562.28418479
32 Su, J.A., C.C. Chang, Y.H. Yang, C.P. Lee, et al., Neonatal and pregnancy complications following maternal depression or antidepressant exposure: A population-based, retrospective birth cohort study. Asian J Psychiatr, 2023. 84: p. 103545.37004384
33 Vlenterie, R., M. van Gelder, H.R. Anderson, L. Andersson, et al., Associations Between Maternal Depression, Antidepressant Use During Pregnancy, and Adverse Pregnancy Outcomes: An Individual Participant Data Meta-analysis. Obstet Gynecol, 2021. 138(4): p. 633-646.34623076
34 Evidence-Based Clinical Practice Guidelines for Prevention, Screening and Treatment of Peripartum Depression. 2025 14 May 2025]; Available from: https://riseupppd18138.com/clinical-practice-guidelines-html/.
35 Amitriptyline, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000233.
36 Uguz, F., A New Safety Scoring System for the Use of Psychotropic Drugs During Lactation. Am J Ther, 2021. 28(1): p. e118-e126.30601177
37 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399-401.29134625
38 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154-170.31544239
39 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215-223.27441996
40 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256-63.8287064
41 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6-13.15492763
42 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*3 [Cited 8 October 2015]. Available from http://www.pharmgkb.org/haplotype/PA165816578.
43 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*4 [Cited 26 Sept 2016]. Available from http://www.pharmgkb.org/haplotype/PA165816579.
44 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 26 Sept 2016]. Available from http://www.pharmgkb.org/haplotype/PA165816582.
45 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229-43.11972444
46 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
47 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and the European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021. 23(9): p. 1047-1064.34118403
48 Koopmans, A.B., M.H. Braakman, D.J. Vinkers, H.W. Hoek, and P.N. van Harten, Meta-analysis of probability estimates of worldwide variation of CYP2D6 and CYP2C19. Transl Psychiatry, 2021. 11(1): p. 141.33627619
49 LLerena, A., M.E. Naranjo, F. Rodrigues-Soares, L.E.M. Penas, et al., Interethnic variability of CYP2D6 alleles and of predicted and measured metabolic phenotypes across world populations. Expert Opin Drug Metab Toxicol, 2014. 10(11): p. 1569-83.25316321
50 Ingelman-Sundberg, M., Pharmacogenetics: an opportunity for a safer and more efficient pharmacotherapy. J Intern Med, 2001. 250(3): p. 186-200.11555122
51 Aklillu, E., K. Herrlin, L.L. Gustafsson, L. Bertilsson, and M. Ingelman-Sundberg, Evidence for environmental influence on CYP2D6-catalysed debrisoquine hydroxylation as demonstrated by phenotyping and genotyping of Ethiopians living in Ethiopia or in Sweden. Pharmacogenetics, 2002. 12(5): p. 375-83.12142727
52 US FDA. Drug Development and Drug Interactions | Table of Substrates, Inhibitors and Inducers. 2023 5 June 2023 7 June 2024]; Available from: https://www.fda.gov/drugs/drug-interactions-labeling/drug-development-and-drug-interactions-table-substrates-inhibitors-and-inducers.
53 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842-1850.30670877
54 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933-939.29882961
55 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024. 29(11): p. 3495-3502.38783055
56 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
57 Scherf-Clavel, M., A. Frantz, A. Eckert, H. Weber, et al., Effect of CYP2D6 pharmacogenetic phenotype and phenoconversion on serum concentrations of antidepressants and antipsychotics: a retrospective cohort study. Int J Clin Pharm, 2023. 45(5): p. 1107-1117.37166747
58 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677-687.34231197
59 Moriyama, B., A.O. Obeng, J. Barbarino, S.R. Penzak, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guidelines for CYP2C19 and Voriconazole Therapy. Clin Pharmacol Ther, 2016.27981572
60 dbSNP. rs3758581 RefSNP Report. 14 Oct 2022]; Available from: https://www.ncbi.nlm.nih.gov/snp/rs3758581.
61 ClinVar. [VCV000039354.3]. 14 Oct 2022]; Available from: https://www.ncbi.nlm.nih.gov/clinvar/variation/VCV000039354.3.
62 PharmVar. CYP2C19. 14 Oct 2022]; Available from: https://www.pharmvar.org/gene/CYP2C19.
63 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, and T.E. Klein, Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542-545.34091888
64 Gene-specific Information Tables for CYP2C19, CYP2C19 Diplotype-Phenotype Table [Cited 23 Jan 2025]. Available from https://www.pharmgkb.org/page/cyp2c19RefMaterials.
65 CYP2C19 allele functionality table [Cited 30 Sept 2022]. Available from https://files.cpicpgx.org/data/report/current/allele_function_reference/CYP2C19_allele_functionality_reference.xlsx.
66 CYP2C19 frequency table [Cited 29 Sept 2022]. Available from https://files.cpicpgx.org/data/report/current/frequency/CYP2C19_frequency_table.xlsx.
67 Alrajeh, K.Y. and Y.M. Roman, The frequency of major CYP2C19 genetic polymorphisms in women of Asian, Native Hawaiian and Pacific Islander subgroups. Per Med, 2022. 19(4): p. 327-339.35748236
68 Scott, S.A., K. Sangkuhl, C.M. Stein, J.S. Hulot, et al., Clinical Pharmacogenetics Implementation Consortium guidelines for CYP2C19 genotype and clopidogrel therapy: 2013 update. Clin Pharmacol Ther, 2013. 94(3): p. 317-23.23698643
69 Pratt, V.M., A.L. Del Tredici, H. Hachad, Y. Ji, et al., Recommendations for Clinical CYP2C19 Genotyping Allele Selection: A Report of the Association for Molecular Pathology. J Mol Diagn, 2018. 20(3): p. 269-276.29474986
70 US Food and Drug Administration. For Healthcare Professionals | FDA’s Examples of Drugs that Interact with CYP Enzymes and Transporter Systems. 2024 24 June 2024 23 Jan 2025]; Available from: https://www.fda.gov/drugs/drug-interactions-labeling/healthcare-professionals-fdas-examples-drugs-interact-cyp-enzymes-and-transporter-systems.
71 Gelbenegger, G. and B. Jilma, Clinical pharmacology of antiplatelet drugs. Expert Rev Clin Pharmacol, 2022: p. 1-21.36065676
72 von Moltke, L.L., D.J. Greenblatt, G.M. Giancarlo, B.W. Granda, et al., Escitalopram (S-citalopram) and its metabolites in vitro: cytochromes mediating biotransformation, inhibitory effects, and comparison to R-citalopram. Drug Metab Dispos, 2001. 29(8): p. 1102-9.11454728
73 EPIDIOLEX- cannabidiol solution. Palo Alto, CA, USA: Jazz Pharamceuticals Inc.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=8bf27097-4870-43fb-94f0-f3d0871d1eec.
74 Jiang, R., S. Yamaori, Y. Okamoto, I. Yamamoto, and K. Watanabe, Cannabidiol is a potent inhibitor of the catalytic activity of cytochrome P450 2C19. Drug Metab Pharmacokinet, 2013. 28(4): p. 332-8.23318708
75 Nanan, J.C., S. Crosby, and M.J. Schuh, Hyponatremic Cognitive Dysfunction Resulting from Drug-Drug-Gene Interaction between Sertraline and Cannabidiol in an Intermediate CYP2C19 Metabolizer Patient. Innov Pharm, 2022. 13(3).36627907
76 Scherf-Clavel, M., H. Weber, S. Unterecker, A. Frantz, et al., The Relevance of Integrating CYP2C19 Phenoconversion Effects into Clinical Pharmacogenetics. Pharmacopsychiatry, 2024. 57(2): p. 69-77.38354747
77 Koepsell, H., Organic Cation Transporters in Health and Disease. Pharmacol Rev, 2020. 72(1): p. 253-319.31852803
78 Matthaei, J., J. Brockmoller, W. Steimer, K. Pischa, et al., Effects of Genetic Polymorphism in CYP2D6, CYP2C19, and the Organic Cation Transporter OCT1 on Amitriptyline Pharmacokinetics in Healthy Volunteers and Depressive Disorder Patients. Front Pharmacol, 2021. 12: p. 688950.34093211
79 Milosavljevic, F., N. Bukvic, Z. Pavlovic, C. Miljevic, et al., Association of CYP2C19 and CYP2D6 Poor and Intermediate Metabolizer Status With Antidepressant and Antipsychotic Exposure: A Systematic Review and Meta-analysis. JAMA Psychiatry, 2021. 78(3): p. 270-280.33237321
80 Halling, J., P. Weihe, and K. Brosen, The CYP2D6 polymorphism in relation to the metabolism of amitriptyline and nortriptyline in the Faroese population. Br J Clin Pharmacol, 2008. 65(1): p. 134-8.17764479
81 van der Weide, J., E.H. van Baalen-Benedek, and J.E. Kootstra-Ros, Metabolic ratios of psychotropics as indication of cytochrome P450 2D6/2C19 genotype. Ther Drug Monit, 2005. 27(4): p. 478-83.16044105
82 Jiang, Z.P., Y. Shu, X.P. Chen, S.L. Huang, et al., The role of CYP2C19 in amitriptyline N-demethylation in Chinese subjects. Eur J Clin Pharmacol, 2002. 58(2): p. 109-13.12012142
83 de Vos, A., J. van der Weide, and H.M. Loovers, Association between CYP2C19*17 and metabolism of amitriptyline, citalopram and clomipramine in Dutch hospitalized patients. Pharmacogenomics J, 2011. 11(5): p. 359-67.20531370
84 Shimoda, K., T. Someya, A. Yokono, S. Morita, et al., The impact of CYP2C19 and CYP2D6 genotypes on metabolism of amitriptyline in Japanese psychiatric patients. J Clin Psychopharmacol, 2002. 22(4): p. 371-8.12172336
85 Joas, E., L. Jonsson, A. Viktorin, E. Smedler, et al., Effect of CYP2C19 polymorphisms on antidepressant prescription patterns and treatment emergent mania in bipolar disorder. Pharmacogenomics J, 2023. 23(1): p. 28-35.36333412
86 Maruf, A.A., A. Greenslade, P.D. Arnold, and C. Bousman, Antidepressant pharmacogenetics in children and young adults: A systematic review. J Affect Disord, 2019. 254: p. 98-108.31112844
87 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.34118403
88 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127-34.25974703
89 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, and C. Ryan, Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89-99.35194175
90 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094-3118.34474980
91 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347-356.36739136
92 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116-3125.37277227
93 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564-9.26931183

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.

## Related Summaries by Gene

Aripiprazole Therapy and CYP2D6 Genotype

Atomoxetine Therapy and CYP2D6 Genotype

Brivaracetam Therapy and CYP2C19 Genotype

CYP2D6 Overview: Allele and Phenotype Frequencies

Carisoprodol Therapy and CYP2C19 Genotype

Carvedilol Therapy and CYP2D6 Genotype

Clobazam Therapy and CYP2C19 Genotype

Clopidogrel Therapy and CYP2C19 Genotype

Clozapine Therapy and CYP Genotype

Codeine Therapy and CYP2D6 Genotype

Deutetrabenazine Therapy and CYP2D6 Genotype

Diazepam Therapy and CYP2C19 Genotype

Eliglustat Therapy and CYP2D6 Genotype

Esomeprazole Therapy and CYP2C19 Genotype

Flibanserin Therapy and CYP2C19 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Lacosamide Therapy and CYP2C19 Genotype

Metoprolol Therapy and CYP2D6 Genotype

Omeprazole Therapy and CYP2C19 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Prasugrel Therapy and CYP Genotype

Primaquine Therapy and G6PD and CYP2D6 Genotype

Propafenone Therapy and CYP2D6 Genotype

Risperidone Therapy and CYP2D6 Genotype

Tamoxifen Therapy and CYP2D6 Genotype

Thioridazine Therapy and CYP2D6 Genotypes

Tramadol Therapy and CYP2D6 Genotype

Valbenazine Therapy and CYP2D6 Genotype

Venlafaxine Therapy and CYP2D6 Genotype

Voriconazole Therapy and CYP2C19 Genotype

## Tests in GTR by Condition

Amitriptyline response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN176769&term=CN176769[DISCUI]&display_string=Amitriptyline response)

## Tests in GTR by Gene

CYP2C19 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1557[geneid]+AND+CN176769[cui])

CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1565[geneid]+AND+CN176769[cui])