# Acknowledgements

## National Institutes of Health (NIH) Contributors

### National Center for Biotechnology Information, National Library of Medicine

Megan S. Kane, PhD

Medical Genetics Curator

Author, Medical Genetics Summaries

Marilu Hoeppner, PhD

Staff Scientist, NIH Genetic Testing Registry

Adriana Malheiro, MS, CGC

Director, NIH Genetic Testing Registry

Editor-in-Chief, Medical Genetics Summaries

Brandi Kattman, MS, CGC

Chief, Medical Genetics and Human Variation Department

## Pharmacogenomics Resources

ClinPGx: ClinPGx (https://www.clinpgx.org/)(Previously operating as: Pharmacogenomics Knowledge Database and Clinical Pharmacogenetics Implementation Consortium)

Pharmacogene Variation Consortium: PharmVar (https://www.pharmvar.org/)

Pharmacogenomics Research Network: PGRN (https://www.pgrn.org/)

Dutch Pharmacogenetics Working Group, Royal Dutch Pharmacists Association: DPWG (https://www.knmp.nl/dossiers/farmacogenetica), DPWG (English language) (https://www.knmp.nl/dossiers/farmacogenetica/pharmacogenetics)

Canadian Pharmacogenomics Network for Drug Safety: CPNDS (http://cpnds.ubc.ca/)

## Drug Regulatory Agency Resources

U.S. Food and Drug Administration (FDA)

Table of Pharmacogenomic Biomarkers in Drug Labeling (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling)

FDA-Approved Drug Labels (DailyMed) (https://dailymed.nlm.nih.gov/dailymed/)

European Medicines Agency (EMA)

Pharmacogenomics Working Party (https://www.ema.europa.eu/en/committees/working-parties-other-groups/chmp/pharmacogenomics-working-party)

## Expert Reviewers

A full list of the Medical Genetics Summaries Expert Reviewers is available here.

## Previous Contributors

Howard McLeod, PharmD

Editor: 2012-2020

Affiliation during editorial tenure:

Medical Director, The DeBartolo Family Personalized Medicine Institute

Senior Member, Division of Population Sciences

Moffitt Cancer Center, Tampa, FL 33612

Wendy Rubenstein, MD, PhD

Editor: 2012-2020

Affiliation during editorial tenure:

Division Director, Clinical Data Management and Curation

CancerLinQ LLC, Alexandria, VA

Laura C. Dean, MD

Author and Editor: 2012-2020

Affiliation during tenure:

Senior Medical Writer, Medical Genetics and Human Variation, National Center for Biotechnology Information (NCBI), National Library of Medicine, National Institutes of Health

Bethesda, MD 20894

Donna Maglott, PhD

Contributor: 2012-2024

Affiliation during tenure:

Senior Staff Scientist, Medical Genetics and Human Variation, National Center for Biotechnology Information (NCBI), National Library of Medicine, National Institutes of Health

Bethesda, MD 20894