# Abacavir Therapy and HLA-B*57:01 Genotype

## Introduction

Abacavir (brand name Ziagen) is used in the treatment of human immunodeficiency virus (HIV) infection. Abacavir is a nucleoside (and nucleotide) reverse transcriptase inhibitor (NRTI), and is used in combination with other medications as part of antiretroviral therapy (ART) (1).

Hypersensitivity reactions associated with abacavir can be severe and potentially fatal. Symptoms include fever, rash, vomiting, and shortness of breath. They typically appear within the first 42 days of treatment (9 days median onset). (1) HLA-B*57:01 significantly increases the risk of hypersensitivity reactions when abacavir is administered.

Screening for the HLA-B*57:01 allele before starting abacavir therapy is recommended for all individuals according to the FDA drug label for abacavir (Table 1) (1). Abacavir is contraindicated in HLA-B*57:01-positive individuals, and in individuals with a prior hypersensitivity reaction to abacavir. Even if previously tolerated, screening should happen before restarting abacavir therapy if HLA-B*57:01 status is unknown. Abacavir therapy should be permanently discontinued if hypersensitivity is suspected. (1)

Guidelines from the professional societies Clinical Pharmacogenetics Implementation Consortium (CPIC) and the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP) also recommend that HLA-B*57:01 screening should be performed before initiation of abacavir therapy and an alternate drug be administered for individuals with the allele (Table 2, Table 3)(2, 3, 4).

Globally, there is wide variability in the frequency of this allele in the human leukocyte antigen B (HLA-B) gene, with estimates ranging from less than 1% to more than 10% (5). The HLA-B gene plays an important role in how the immune system recognizes and responds to pathogens and mediates hypersensitivity reactions. HLA-B*57:01 has been found to be associated with abacavir hypersensitivity across different ethnicities, including Caucasians, Hispanics, and individuals of African origin (3, 6).

Table 1.

Abacavir Therapeutic Recommendations based on HLA-B*57:01 Genotype, FDA (2025)

Genotype | Hypersensitivity reactions
HLA-B*57:01-positive individuals | Due to the potential for severe, serious, and possibly fatal hypersensitivity reactions with abacavir sulfate: All individuals should be screened for the HLA-B*57:01 allele prior to initiating therapy with abacavir tablets or reinitiation of therapy with abacavir tablets, unless individuals have a previously documented HLA-B*57:01 allele assessment. Abacavir tablets are contraindicated in individuals with a prior hypersensitivity reaction to abacavir and in HLA-B*57:01-positive individuals.

Table adapted from (1).

Table 2.

Recommendations for Abacavir based on HLA-B Genotype, DPWG (2024)

Genotype | Recommendation
HLA-B*57:01-positive | Abacavir is contraindicated for HLA-B*57:01-positive individuals, avoid abacavir

Table adapted from (4, 7). HLA-B*57:01: abacavir recommendations last updated February 7, 2023, still valid in 2024 published document.

Table 3.

Recommended Therapeutic Use of Abacavir in relation to HLA-B Genotype^a^, CPIC (2014)

Genotype | Implications for phenotypic measures | Recommendations for abacavir | Classification of recommendations^b^
“Negative” Noncarrier of HLA-B*57:01 | Low or reduced risk of abacavir hypersensitivity | Use abacavir per standard dosing guidelines | Strong
“Positive” Carrier of HLA-B*57:01 | Significantly increased risk of abacavir hypersensitivity | Abacavir is not recommended | Strong

HLA-B, human leukocyte antigen B.

^a^ The 2014 update states that the recommendations shown in the table from the 2012 guideline remain the same. This table has been adapted from the 2012 guideline (2 , 3).

^b^ Rating scheme described in supplementary data online (2 , 3).

Table adapted from (3).

## Drug: Abacavir

Abacavir is an antiretroviral drug that belongs to the drug class of nucleoside (and nucleotide) reverse transcriptase inhibitors (NRTIs). The NRTIs, also known as nucleoside (or nucleotide) analogs, were the first type of drug available to treat HIV infection, and they remain effective today. In addition to abacavir, NRTIs include drugs such as AZT/zidovudine, emtricitabine, tenofovir, and lamivudine. HIV practice guidelines recommend a combination therapy approach to achieve effective viral suppression, and as such abacavir, when clinically indicated, should be used in combination with other drugs (8, 9).Current guidelines do not list abacavir as a first-line therapy component, recommending it only for a subset of clinical scenarios (8).

Antiretroviral drugs, like abacavir, inhibit the activity of retroviruses, such as HIV. To replicate, retroviruses must convert their RNA genome into a DNA copy, which can then be inserted into the host cell’s genome. Abacavir inhibits the conversion of viral RNA to DNA, preventing viral replication.

Abacavir is a pro-drug and its antiviral activity is facilitated by the drug’s phosphorylation by intracellular enzymes to form carbovir triphosphate, a nucleoside analog. Carbovir triphosphate competes with the natural substrate of the HIV reverse transcriptase enzyme, to be incorporated into viral DNA. Once incorporated, the nucleoside analog terminates DNA chain elongation, preventing further synthesis of viral DNA (10).

Abacavir was first approved by the FDA in 1998, as part of a combination of therapies to treat HIV. However, the use of abacavir in the US was limited by a severe hypersensitivity reaction that occurred in approximately 5–8% of individuals (11). Symptoms occurred during the first 6 weeks and included a constellation of symptoms presenting as rash, fever, fatigue, gastrointestinal symptoms (for example, nausea, vomiting, abdominal pain), and acute respiratory symptoms (for example, cough and dyspnea) (12). Life-threatening skin diseases, Stevens-Johnson syndrome and toxic-epidermal necrolysis, have been reported when abacavir is used with other medications that are known to be associated with these reactions (1). Stevens-Johnson syndrome has been reported in one case with abacavir-containing ART but showed no reaction to rechallenge with the other medications (13). These represent known Type B hypersensitivity reactions, ones that occur independent of specific drug properties or mechanism of action (14).

Data from the PREDICT-1 study suggest that 100% of individuals with immunologically confirmed (abacavir patch test positive) abacavir hypersensitivity present within 6 weeks of initial dosing. The median onset of symptoms is 9 days (1). This hypersensitivity reaction has been found to correlate with individuals having an HLA-B*57:01 allele, though individuals without the allele may also experience the adverse reactions (1, 15, 16).

Presence of the HLA-B*57:01 allele confers a dramatic increase in risk of abacavir hypersensitivity reactions and this association has led to boxed warnings on drug labeling from the FDA, European Medicines Agency, Health Canada and other international regulatory bodies (1, 15, 16, 17, 18). Clinical practice guidelines also strongly recommend the use of HLA testing prior to initiation of abacavir therapy (2, 4, 8, 19, 20, 21). However, a recent study has indicated the utilization of pharmacogenetic testing for HLA-B*57:01 has decreased since 2018 among individuals prescribed abacavir in the US (22).

Additional adverse reactions with abacavir have been reported. These Type A reactions result from known pharmacologic properties of the medication and its clinical effect (14). The FDA-approved drug label includes warnings for lactic acidosis and severe hepatomegaly with steatosis, immune reconstitution syndrome, and myocardial infarction. Lactic acidosis and hepatomegaly cases have been most frequently reported in women; abacavir therapy should be suspended in any individual with clinical or laboratory findings suggestive of lactic acidosis or hepatotoxicity. Immune reconstitution syndrome has been observed following effective combination antiretroviral therapy, including abacavir, in response to indolent or opportunistic infections in the previously immunocompromised individuals. The mechanism underlying the observed association of abacavir therapy and risk of myocardial infarction is unknown; clinicians are advised to take precautions when prescribing abacavir and to consider underlying coronary heart disease. (1)

Use of abacavir during pregnancy has not been shown to cause any increase in the risk of birth defects as compared to the general population (1). It is recommended as an alternative rather than preferred antiretroviral medication during pregnancy due to the need to perform HLA-B genotyping and concerns over cardiac safety (9). Abacavir does cross the placenta and neonates have been found to have similar blood plasma levels as their mother at the time of delivery (1). A large meta-analysis of NRTI-containing ART use in pregnant women reported no adverse perinatal outcomes with abacavir (23). Abacavir can be secreted into breast milk in small quantities, however mothers who are HIV positive with a quantifiable plasma viral load are not recommended to breastfeed due to risk of viral transmission (24). Even with viral suppression, there is a non-zero risk of HIV transmission from a breastfeeding mother to infant and there are only limited case studies describing outcomes for infants breastfed while the mother continued ART with abacavir (24).

Abacavir has been determined by the FDA to be safe and effective in children 3 months and older, with similar rates of adverse effects observed in pediatric and adult clinical trials (1). The EMA and Health Canada have similarly approved abacavir for individuals as young as 3 months of age (15, 17). There is insufficient data to determine if adults over 65 years of age respond differently to abacavir than younger adults, thus the FDA advises a generally cautious approach to use of abacavir in older adults based on decreased hepatic, renal, or cardiac function that is often seen in this population. (1)

## HLA Gene Family

The HLA genes are members of the major histocompatibility complex (MHC) gene family, which includes more than 200 genes. The HLA region also contains a variety of other genes, including genes involved in immunity and genes not known to be involved in immune function. The MHC family has been subdivided into 3 subgroups based on the structure and function of the encoded proteins: class I, class II, and class III. The class I region contains the genes encoding the HLA molecules HLA-A, HLA-B, and HLA-C. These molecules are expressed on the surfaces of almost all cells and play an important role in antigen presentation.

An important role of HLA class I molecules is to present peptides (processed fragments of antigens) to immune cells (CD8^+^ T cells). Most of these peptides originate from the breakdown of normal cellular proteins (“self”). However, if foreign peptide fragments are presented, for example, from a pathogen, CD8^+^T cells will recognize the peptides as “non-self” and will be activated to release inflammatory cytokines and launch an immune response to dispose of the pathogen (or foreign body).

Because HLA molecules need to present such a wide variety of “self” and “non-self” peptides, the HLA genes are both numerous and highly polymorphic. Thousands of HLA-B alleles have been identified (10, 25).

### HLA Allele Nomenclature

HLA allele nomenclature includes the HLA prefix, followed by the gene, an asterisk and a 4 (or 6) digit number that corresponds to the assigned allele number (26, 27). For example, the HLA-B*15:02: allele is composed of:

- HLA: the HLA prefix (the HLA region on chromosome 6)
- B: the B gene (a particular HLA gene in this region)
- 15: the allele group (historically determined by serotyping, namely, a group of alleles that share the same serotype)
- 02: the specific HLA allele (a specific protein sequence; determined by genetic analysis).

Additional digits have been added to the nomenclature to discriminate between alleles that do not differ in the protein amino acid sequence but differ in their genetic sequence (namely due to synonymous and noncoding genetic variants).

Variation in HLA genes plays an important role in susceptibility to autoimmune disease and infections. These variations are also critical in the context of transplant surgery where better outcomes are observed if the donor and recipient are HLA-compatible.

Genetic variants in the HLA genes have also been associated with susceptibility to Type B (such as hypersensitivity) adverse drug reactions. For example, as noted above, an HLA-B variant has been associated with severe hypersensitivity reactions to abacavir. Other HLA-B variants have been associated with severe reactions to allopurinol (used to treat gout), and carbamazepine and phenytoin (used to treat epilepsy).

## Gene: HLA-B

The HLA-B protein is an HLA class I heavy chain paralog, it forms a heterodimer made up of a heavy chain and light chain. It is encoded on chromosome 6 (p21.33) by the HLA-B locus, which is highly polymorphic (28). Several HLA-B variants are associated with adverse pharmacologic responses and immune reactions. Alleles involved in abnormal pharmacogenetic responses, such as drug hypersensitivity, Stevens-Johnson syndrome, and other cutaneous reactions, include HLA-B *15:11, *58:01, *15:02, *57:01, with further evidence suggesting additional risk alleles (for example HLA-B*13:01 and dapsone) (29).

The HLA-B*57:01 allele also has an important role in HIV infection. In Caucasians with HIV, HLA-B*57:01 has been linked to a lower viral load set point (the amount of viral RNA detected in blood during the asymptomatic phase of HIV infection) (30). In addition, HLA-B*57:01 is overrepresented in a small group of individuals who have HIV which has not progressed to AIDS, despite lack of treatment with ART. These individuals are known as “long-term non-progressors” (31). Additional studies have evaluated this allele on HIV1 control, finding that individuals with HLA-B*57:01 allele had better virological responses to antiretroviral therapy (32). This may be due to a broader genetic haploblock that is associated with this allele, rather than the specific functional effects on antigen-presentation of the HLA variant (33).

The frequency of the HLA-B*57:01 allele varies significantly by population (Table 4). The allele is quite common in Indian populations (up to 11%). It is relatively common in European populations (6–7%), and) and is present but less common in African Americans (2–3%), admixed American populations, and Middle Eastern populations (2–3%). HLA-B*57:01 is rare in many East-Asian and African populations, being mostly absent in the Japanese (3 , 6). Despite the wide range of allele frequencies, clinical practice guidelines recommend testing in all individuals prior to abacavir therapy to reduce the risk of adverse reactions (8, 9, 20).

Table 4.

HLA-B*57:01 Reported Allele Frequencies

Country/people group studied | Reported HLA-B*57:01 frequency | Number of individuals in study | Citation
Uganda | 3.1% | (Review article)^a^ | (5)
Nigeria | 1.65% | 364 | (34)
Sudan | 1.5% | (Review article) | (5)
West and Central Africa | 0.10% | 4,016 | (35)
Benin | 0.00% | 110 | (36)
Mali | 0.00% | (Review article) | (5)
Greater Middle East | 1–3% | (Review article) | (37)
Jordan | 2.60% | 76 | (38)
Kuwait | 1.07% | 561 | (39)
Turkey | 1.60% | 867 | (40)
Israel | 2.4% | (Review article) | (5)
Saudi Arabia | 0.2% | (Review article) | (5)
Sri Lanka | 9.3% | (Review article) | (5)
India | 6.2% | (Review article) | (5)
India (pediatric population) | 11.0% | 100 | (41)
Singapore | 1.0% | (Review article) | (5)
Malaysia | 0.66% | 152 | (42)
Indonesian Malay | 0.86% | 58 | (43)
Thailand | 1.77% | 470 | (44)
Thailand | 3.33% | 12,425 | (45)
China | 0.6% | (Review article) | (5)
Japan | <0.1% | (Review article) | (5)
South Korea | 0.2% | (Review article) | (5)
Ireland | 5.8% | (Review article) | (5)
Switzerland | 4.6% | (Review article) | (5)
Bulgaria | 4.5% | (Review article) | (5)
Netherlands | 4.46% | 1,347 | (46)
United Kingdom | 4.1% | (Review article) | (5)
Belgium | 2.0% | (Review article) | (5)
Sweden | 1.0% | (Review article) | (5)
Chile | 2.8% | (Review article) | (5)
Columbia | 2.7% | 902 | (47)
Brazil | 1.5% | 96 | (48)
Peru | 0.33% | 300 | (49)
Bolivia | <0.7% | (Review article) | (5)
United States of America | 2.8% | (Review article) | (5)
Cuba | 2.3% | (Review article) | (5)
Australia | 2.7% | (Review article) | (5)
New Zealand | 1.0% | (Review article) | (5)

^a^ Note that sample sizes were not clearly provided in the cited review articles. Values are provided here as a comparison, readers should consult the cited article and country-specific guidelines regarding allele frequency and testing recommendations.

Additional country-specific allele frequencies are provided in (5).

## Linking HLA-B*57:01 with Abacavir Response

Individuals with the HLA-B*57:01 allele have an increased risk of a hypersensitivity reaction to abacavir compared to HLA-B*57:01-negative individuals (50). Initial studies across ethnicities have reported that in immunologically confirmed cases of abacavir hypersensitivity, 100% of cases occurred in individuals who were positive for this HLA variant (12). Other immune factors are also involved, however. For example, not everyone who has the high-risk HLA allele will develop abacavir hypersensitivity - approximately 39% of individuals who are positive for HLA-B*57:01 will tolerate abacavir treatment (50). Other analysis has indicated that the positive predictive value of HLA-B*57:01 and abacavir sensitivity is closer to 50% and the negative predictive value is more than 95% (51).

One study has reported that variation at the ERAP1 locus resulting in a hypoactive enzyme was more frequently found in HLA-B*57:01 positive individuals that tolerated abcavir therapy versus individuals that were hypersensitive (52). The ERAP, or endoplasmic reticulum aminopeptidase, proteins are responsible for trimming the N-terminal of peptides before presentation on HLA class I molecule. Interaction between ERAP and HLA molecules may contribute to the aberrant immune response in a number of conditions, including autoimmune disorders. (52)

Cytotoxic (CD8^+^) T cells mediate the hypersensitivity reaction to abacavir. Abacavir is thought to form a non-covalent complex with HLA-B*57:01 (53, 54, 55, 56). Several theories have been proposed for how this drug peptide-HLA complex activates the T cell receptor, which then releases inflammatory cytokines, signaling the start of the hypersensitivity response (57, 58, 59, 60, 61). More than one immune mechanism may be involved (12). It has been shown that abacavir occupies a space below the region of HLA that presents peptides. This leads to altered peptide presentation (including the presentation of self-peptides to which the host has not been tolerized) and triggers an autoimmune-like reaction (57, 62).

The hypersensitivity reaction to abacavir is thought to be maintained over the lifetime of an individual. The reintroduction of abacavir to a sensitized individual may be fatal, presumably due to a rapid activation of a memory T cell population. Therefore, abacavir is contraindicated in individuals with a prior hypersensitivity reaction to abacavir (1, 63).

The FDA-approved label for abacavir states that all individuals should be screened for the HLA-B*57:01 allele prior to initiating therapy with abacavir, or when reinitiating therapy with abacavir, unless individuals have a previously documented HLA-B*57:01 allele assessment. The FDA also warns that abacavir must be discontinued immediately if a hypersensitivity reaction is suspected, regardless of HLA-B*57:01 status and even when other diagnoses are possible (1).

Several studies have shown that routine genetic screening for HLA-B*57:01 significantly reduces the incidence of abacavir-induced hypersensitivity and is cost-effective. Because it is rare for individuals who do not have the high-risk HLA variant to develop hypersensitivity, adhering to the screening guidelines can reduce the incidence of immunologically confirmed cases of abacavir hypersensitivity to nearly zero (64, 65, 66, 67).

## Genetic Testing

Pharmacogenetic testing for HLA-B*57:01 is readily available in clinical practice laboratories (68).The NIH’s Genetic Testing Registry (GTR) provides examples of the genetic tests that are available for abacavir hypersensitivity (https://www.ncbi.nlm.nih.gov/sites/gtr/all/tests/?term=C1840547), and the HLA-B (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=3106%5Bgeneid%5D) gene.

The genotype results for an HLA allele such as HLA-B*57:01 can either be “positive” or “negative” (Table 5). There are no intermediate phenotypes because the HLA genes are expressed in a codominant manner.

Table 5.

CPIC (2014) Assignment of likely HLA-B Phenotypes based on Genotype

Likely phenotype | Genotype | Examples of diplotype
Very low risk of hypersensitivity (constitutes ~94%^a^ of individuals) | Absence of *57:01 alleles (reported as “negative” on a genotyping test) | *X/*X^b^
High risk of hypersensitivity (~6% of individuals) | Presence of at least one *57:01 allele (reported as “positive” on a genotyping test) | *57:01/*X^b^ *57:01/*57:01

HLA-B, human leukocyte antigen B.

^a^ See supplementary data online for estimates of genotype frequencies among different ethnic/geographic groups.

^b^ *X = any HLA-B genotype other than *57:01.

Table adapted from (3).

The testing methodology for detecting the variant allele often utilizes SSP (specific sequence PCR amplification) or SSOP (PCR amplification of the target HLA-B gene region followed by oligonucleotide hybridization). DNA sequence analysis of specific exons or the entire gene is also commonly used. Additional techniques for resource-limited settings have also been investigated, such as nested PCR or sequence-based typing for surrogate allele markers (69). Methods to develop a point-of-care testing using peripheral blood samples and expression of the HLA-B allele have also been described as well (70).

Abacavir is contraindicated in individuals with a “positive” result, and only one copy of the *57:01 allele is required for a positive result. Therefore, the positive result is either “heterozygous” or “homozygous”, depending upon whether the individual has one or 2 copies of the *57:01 allele. Adopting routine HLA-B*57:01 testing has resulted in a decreased frequency of abacavir hypersensitivity in multiple reports (45, 71).

A negative result indicates that the individual does not have the HLA-B*57:0 allele. However, a negative result does not rule out the possibility of an individual developing abacavir hypersensitivity. Therefore, clinicians should carefully monitor all individuals according to standard practices (3, 72).

Confirmation of abacavir hypersensitivity in an individual can be performed, as well. The procedure consists of an epicutaneous patch test after the individual has previously been exposed to abacavir (11). Ideally, experts recommend screening for the HLA-B*57:01 allele prior to therapy with abacavir and state that rechallenge with the medication should not be attempted for individuals with a documented history compatible with abacavir hypersensitivity reaction (72). Skin patch testing may be utilized for individuals with a history of a possible hypersensitivity reaction, but cannot be used on treatment-naïve individuals, as the test requires immunologic “priming” by previous systemic exposure (72).

## The HLA-B Gene Interactions with Medications Used for Additional Indications

The HLA loci can influence several physiological responses, including aberrant immune responses to prescribed medications. Alleles at the HLA-B locus have been associated with abnormal reactions to multiple types of medications including:

- Antibiotics: flucloxacillin can cause drug-induced liver injury which has a strong association with HLA-B*57:01 (4, 73, 74)
- Chemotherapy with tyrosine kinase inhibitor: pazopanib may be associated with a higher risk of liver injury in HLA-B*57:01-positive individuals (75)

Additional information on gene-drug interactions for HLA-B are available from ClinPGx (https://www.clinpgx.org/gene/PA35056), CPIC (https://cpicpgx.org/genes-drugs/) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “HLA-B”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene^2^-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2025 Statement From the US Food and Drug Administration (FDA)

Serious and sometimes fatal hypersensitivity reactions have occurred with abacavir. These hypersensitivity reactions have included multi-organ failure and anaphylaxis and typically occurred within the first 6 weeks of treatment with abacavir (median time to onset was 9 days); although abacavir hypersensitivity reactions have occurred [at] any time during treatment. Patients who carry the HLA-B*57:012 allele are at a higher risk of abacavir hypersensitivity reactions; although, patients who do not carry the HLA-B*57:01 allele have developed hypersensitivity reactions.

Hypersensitivity to abacavir was reported in approximately 206 (8%) of 2,670 patients in 9 clinical trials with abacavir-containing products where HLA-B*57:01 screening was not performed. The incidence of suspected abacavir hypersensitivity reactions in clinical trials was 1% when subjects carrying the HLA-B*57:01 allele were excluded. In any patient treated with abacavir, the clinical diagnosis of hypersensitivity reaction must remain the basis of clinical decision making.

Due to the potential for severe, serious, and possibly fatal hypersensitivity reactions with abacavir:

• All patients should be screened for the HLA-B*57:01 allele prior to initiating therapy with abacavir or reinitiation of therapy with abacavir, unless patients have a previously documented HLA-B*57:01 allele assessment.

• Abacavir [is] contraindicated in patients with a prior hypersensitivity reaction to abacavir and in HLA-B*57:01-positive patients.

• Before starting abacavir, review medical history for prior exposure to any abacavir containing product. NEVER restart abacavir or any other abacavir-containing product following a hypersensitivity reaction to abacavir, regardless of HLA-B*57:01 status.

• To reduce the risk of a life-threatening hypersensitivity reaction, regardless of HLA-B*57:01 status, discontinue abacavir immediately if a hypersensitivity reaction is suspected, even when other diagnoses are possible (e.g., acute onset respiratory diseases such as pneumonia, bronchitis, pharyngitis, or influenza; gastroenteritis; or reactions to other medications).

• If a hypersensitivity reaction cannot be ruled out, do not restart abacavir or any other abacavir-containing products because more severe symptoms which may include life threatening hypotension and death, can occur within hours.

• If a hypersensitivity reaction is ruled out, patients may restart abacavir. Rarely, patients who have stopped abacavir for reasons other than symptoms of hypersensitivity have also experienced life-threatening reactions within hours of reinitiating abacavir therapy. Therefore, reintroduction of abacavir or any other abacavir containing product is recommended only if medical care can be readily accessed.

• A Medication Guide and Warning Card that provide information about recognition of hypersensitivity reactions should be dispensed with each new prescription and refill.

Please review the complete therapeutic recommendations that are located here: (1).

### 2014 Statement From the Clinical Pharmacogenetics Implementation Consortium (CPIC)

We agree with others that HLA-B*57:01 screening should be performed in all abacavir-naive individuals before initiation of abacavir-containing therapy (see Table 2); this is consistent with the recommendations of the FDA, the US Department of Health and Human Services, and the European Medicines Agency. In abacavir-naive individuals who are HLA-B*57:01-positive, abacavir is not recommended and should be considered only under exceptional circumstances when the potential benefit, based on resistance patterns and treatment history, outweighs the risk. HLA-B*57:01 genotyping is widely available in the developed world and is considered the standard of care prior to initiating abacavir. Where HLA-B*57:01 genotyping is not clinically available (such as in resource-limited settings), some have advocated initiating abacavir, provided there is appropriate clinical monitoring and patient counseling about the signs and symptoms of HSR [hypersensitivity reaction], although this remains at the clinician’s discretion.

Please review the complete therapeutic recommendations that are located here (2, 3).

### 2019, 2023 Summary of Recommendations From the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

HLA-B*57:01: abacavir

48% of the HLA-B*57:01-positive patients develop a severe and potentially life-threatening hypersensitivity reaction to abacavir.

Abacavir is contra-indicated for HLA-B*57:01-positive patients.

- avoid abacavir

Recommendation concerning pre-emptive genotyping, including justification of choices:

The KNMP Pharmacogenetics Working Group considers genotyping before starting abacavir to be essential for drug safety. Genotyping must be performed before drug therapy has been initiated to guide drug selection. The clinical implication of the gene-drug interaction scores 9 out of the maximum of 10 points (with pre-emptive genotyping considered to be essential for scores ranging from 6 to 10 points) (see also the two tables at the end of this risk analysis):

The risk of serious and possibly life-threatening abacavir hypersensitivity reactions is increased for carriers of HLA-B*57:01. The SmPC indicates that abacavir-induced hypersensitivity reaction can be fatal (severity code F, corresponding to CTCAE grade 5). This results in the maximum of 2 points for the first criterion of the clinical implication score, the clinical effect associated with the gene-drug interaction (2 points for CTCAE grade 5).

The increased risk for serious life-threatening hypersensitivity reactions (code E corresponding to grade 4) has been shown in 9 studies and 3 meta-analyses and the reduction of these serious life-threatening hypersensitivity reactions by avoiding abacavir in HLA-B*57:01 carriers has been shown in 4 studies and 1 meta-analysis. This results in the maximum score of 3 points for the second criterion of the clinical implication score, the level of evidence supporting the associated clinical effect grade ≥ 3 (3 points for three or more publications with level of evidence score ≥ 3).

[…]

The HLA-B*57:01 carrier prevalence in the Netherlands is 6.7%. Correction for this slightly higher HLA-B*57:01 carrier prevalence, results in a number needed to genotype of 31 in the Dutch population to prevent one patient developing abacavir hypersensitivity. The calculated number to genotype of 31 results in 2 out of the maximum of 3 points for the third criterion of the clinical implication score, the number needed to genotype (NNG) in the Dutch population to prevent one clinical effect grade ≥ 3 (2 points for 10 ≤ NNG ≤ 100).

The Summary of Product Characteristics (SmPC) of abacavir indicates that screening for carriage of the HLA-B*57:01 allele should be performed in any HIV-infected patient, irrespective of racial origin, before initiating treatment with abacavir and that abacavir should not be used in patients known to carry the HLA-B*57:01 allele.

Please review the complete therapeutic recommendations that are located here: ( 4 , 7 ).

## Nomenclature of Selected Alleles

Nomenclature of Selected HLA-B alleles

Common allele name | IPD-IMGT/HLA^a^ allele information | Genomic context^b^
HLA-B*57:01 (http://www.ncbi.nlm.nih.gov/clinvar/variation/14910/) | HLA-B*57:01:01:01 (https://www.ebi.ac.uk/ipd/imgt/hla/alleles/allele/?accession=HLA00381) | 6p21.33; GRCh38.p14 NC_000006.12:31353875-31357179 (-)

^a^ The Immuno Polymorphism Database- ImmunoGenetics project/HLA allele database (IPD-IMGT/HLA) sequence link is provided (76).

^b^ For the MHC region, variations in genes such as HLA-B occur across the whole sequence of the gene, not a single locus. Therefore, the HLA-B*57:01 allele is defined by its sequence (GenBank: AF196183.1 (http://www.ncbi.nlm.nih.gov/nuccore/AF196183)) rather than single coding or protein variants. Genomic location from NCBI Gene (https://www.ncbi.nlm.nih.gov/datasets/gene/3106/).

Historically, tag SNPs have been used for HLA typing (77, 78). However, these have limited utility across diverse genetic ancestries, and their use is not recommended.

Guidelines on the naming of HLA genes are available from HLA Nomenclature (https://hla.alleles.org/).

## Acknowledgments

Version 3 (March 31, 2026): The authors would like to thank Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; J. Rex Astles, PhD, FADLM, Division of Laboratory Systems, Centers for Disease Control and Prevention, Lisa Kalman, PhD, Genetic Testing Reference Material Coordination Program, Division of Laboratory Systems, Centers for Disease Control and Prevention, and Jesse O’Shea, MD, Medical Officer, Centers for Disease Control and Prevention, Atlanta, GA, USA for reviewing this summary.

Version 2 (April 18, 2018): The author would like to thank Inge Holsappel, Pharmacist at the Royal Dutch Pharmacists Association (KNMP), the Netherlands, for reviewing the information regarding the guidelines of the Dutch Pharmacogenetics Working Group (DPWG); David A. Ostrov, PhD, Associate Professor, Department of Pathology, Immunology and Laboratory Medicine, University of Florida College of Medicine; Professor Anthony W. Purcell, Department of Biochemistry and Molecular Biology and Biomedicine Discovery Institute, Monash University, Australia; and Lisa Ross, Director, Clinical Sciences Group at ViiV Healthcare, Durham, North Carolina; for reviewing this summary.

Version 1 (September 1, 2015): The author would like to thank Elizabeth Phillips, MD, FIDSA, John A. Oates Chair in Clinical Research, Professor of Medicine and Pharmacology, Director of Personalized Immunology, Oates Institute for Experimental Therapeutics, Vanderbilt University Medical Center; and Professor Munir Pirmohamed, David Weatherall Chair of Medicine, University of Liverpool and Director of the MRC Centre for Drug Safety Sciences, for reviewing this summary.

## Version History

A minor revision (version 3.1) was published on July 6, 2026 to update the URL for reference 9.

A major update (version 3.0) was published on March 31, 2026 with current FDA labeling and expanded regulatory guidance from Europe and Canada as well as additional information regarding allele frequencies from global populations. Testing and prescribing recommendations from professional societies and other bodies has not changed relative to version 2.

A minor revision (version 2.1) was published on April 21, 2025 to update links to the HLA Nomenclature information cited in the text. No changes were made to the content of the chapter and no changes in practice recommendations were included in the revision.

A major update for this chapter was published on April 18, 2018, version 2.0. To view version 2 of this summary (created April 18, 2018) please click here.

To view the 2015 version of this summary (Created: September 1, 2015, v. 1.0) please click here.

## References

1 ABACAVIR- abacavir tablet. Piscataway, NJ, USA: Camber Pharmaceuticals Inc.; 2025. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=44fb1e25-ad03-4a7f-9f35-2e29f5025661.
2 Martin, M.A., J.M. Hoffman, R.R. Freimuth, T.E. Klein, et al., Clinical Pharmacogenetics Implementation Consortium Guidelines for HLA-B Genotype and Abacavir Dosing: 2014 update. Clin Pharmacol Ther, 2014. 95(5): p. 499–500.24561393
3 Martin, M.A., T.E. Klein, B.J. Dong, M. Pirmohamed, et al., Clinical pharmacogenetics implementation consortium guidelines for HLA-B genotype and abacavir dosing. Clinical pharmacology and therapeutics, 2012. 91(4): p. 734–8.22378157
4 Pharmacogenetic Recommendation Text [Cited Feb. 12, 2026]. Available from https://www.knmp.nl/dossiers/farmacogenetica.
5 Zhou, Y., K. Krebs, L. Milani, and V.M. Lauschke, Global Frequencies of Clinically Important HLA Alleles and Their Implications For the Cost-Effectiveness of Preemptive Pharmacogenetic Testing. Clin Pharmacol Ther, 2021. 109(1): p. 160–174.32535895
6 Sousa-Pinto, B., J. Pinto-Ramos, C. Correia, G. Goncalves-Costa, et al., Pharmacogenetics of abacavir hypersensitivity: A systematic review and meta-analysis of the association with HLA-B*57:01. J Allergy Clin Immunol, 2015. 136(4): p. 1092–4.e3.25934581
7 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. HLA: abacavir [Cited Feb. 17, 2026]. Available from https://www.g-standaard.nl/risicoanalyse/M0002761.pdf.
8 Panel on Antiretroviral Guidelines for Adults and Adolescents. Guidelines for the Use of Antiretrovial Agents in Adults and Adolescents With HIV. 2025 Feb. 12, 2026]; Available from: https://clinicalinfo.hiv.gov/en/guidelines/hiv-clinical-guidelines-adult-and-adolescent-arv/adverse-effects-antiretroviral-agents.
9 Recommendations for the Use of Antiretroviral Drugs During Pregnancy and Interventions to Reduce Perinatal HIV Transmission in the United States [Cited Oct. 1, 2025]. Available from https://clinicalinfo.hiv.gov/en/guidelines/perinatal/recommendations-arv-drugs-pregnancy-prevent-hiv-transmission-improve-health.
10 HLA Nomenclature [Internet]. Royal Free Hospital, London, UK. HLA Nomenclature: HLA Alleles Numbers [Cited 2018 January 09]. Available from https://hla.alleles.org/pages/genes/statistics/
11 Zubair, M. and E.S. Vadakekut, HLA-B*57:01 Testing, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/32809632.
12 Illing, P.T., A.W. Purcell, and J. McCluskey, The role of HLA genes in pharmacogenomics: unravelling HLA associated adverse drug reactions. Immunogenetics, 2017. 69(8-9): p. 617–630.28695285
13 Bossi, P., J.C. Roujeau, F. Bricaire, and E. Caumes, Stevens-Johnson syndrome associated with abacavir therapy. Clin Infect Dis, 2002. 35(7): p. 902.12228837
14 Kommu, S., C. Carter, and P. Whitfield, Adverse Drug Reactions, in StatPearls. 2026: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/38261714.
15 Ziagen : EPAR - Product Information. Amersfoort, Netherlands: ViiV Healthcare BV; 2026. Available from: https://www.ema.europa.eu/en/medicines/human/EPAR/ziagen.
16 Quiros-Roldan, E., G. Gardini, M. Properzi, A. Ferraresi, et al., Abacavir adverse reactions related with HLA-B*57: 01 haplotype in a large cohort of patients infected with HIV. Pharmacogenet Genomics, 2020. 30(8): p. 167–174.32453265
17 APO-Abacavir, Product monograph. Toronto, Ontatio, Canada: Apotex Inc.; 2024. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=88178.
18 Kuruvilla, R., K. Scott, and S.M. Pirmohamed, Pharmacogenomics of Drug Hypersensitivity: Technology and Translation. Immunol Allergy Clin North Am, 2022. 42(2): p. 335–355.35469622
19 Hammer, S.M., J.J. Eron, Jr., P. Reiss, R.T. Schooley, et al., Antiretroviral treatment of adult HIV infection: 2008 recommendations of the International AIDS Society-USA panel. JAMA, 2008. 300(5): p. 555–70.18677028
20 Renac, V., V. Moalic, G. Dautin, M. Cherel, et al., Guidelines From the French-Speaking Society for Histocompatibility and Immunogenetics (SFHI) for Harmonisation of HLA Genotyping in Autoimmune Diseases, Drug Hypersensitivity and Pharmacogenetics. HLA, 2025. 106(4): p. e70442.41137743
21 Gazzard, B.G., J. Anderson, A. Babiker, M. Boffito, et al., British HIV Association Guidelines for the treatment of HIV-1-infected adults with antiretroviral therapy 2008. HIV Med, 2008. 9(8): p. 563–608.18826546
22 Kalman, L.V., Y. Xia, Y.A. Huang, K. Buchacz, et al., Gaps in guideline adherence: evaluating HLA-B*57:01 screening for abacavir sensitivity and the implementation of evidence-based HIV care. Clin Biochem, 2025. 139: p. 110992.40829703
23 Cowdell, I., K. Beck, M. Hey, C. Portwood, et al., Association of nucleoside reverse transcriptase inhibitors with adverse perinatal outcomes in pregnant women living with HIV: systematic review and meta-analysis. Clin Microbiol Infect, 2025. 31(6): p. 958–970.39848582
24 Abacavir, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000607.
25 Robinson, J., D.J. Barker, and S.G.E. Marsh, 25 years of the IPD-IMGT/HLA Database. HLA, 2024. 103(6): p. e15549.38936817
26 Choo, S.Y., The HLA system: genetics, immunology, clinical testing, and clinical implications. Yonsei Med J, 2007. 48(1): p. 11–23.17326240
27 HLA Nomenclature - Naming Alleles [Cited Feb 13, 2026]. Available from https://hla.alleles.org/pages/nomenclature/naming_alleles/.
28 HLA-B major histocompatibility complex, class I, B [ Homo sapiens (human) ] [Cited Feb. 16, 2026]. Available from https://www.ncbi.nlm.nih.gov/gene/3106.
29 Whirl-Carrillo, M., R. Huddart, L. Gong, K. Sangkuhl, et al., An Evidence-Based Framework for Evaluating Pharmacogenomics Knowledge for Personalized Medicine. Clin Pharmacol Ther, 2021. 110(3): p. 563–572.34216021
30 Fellay, J., K.V. Shianna, D. Ge, S. Colombo, et al., A whole-genome association study of major determinants for host control of HIV-1. Science, 2007. 317(5840): p. 944–7.17641165
31 Migueles, S.A., M.S. Sabbaghian, W.L. Shupert, M.P. Bettinotti, et al., HLA B*5701 is highly associated with restriction of virus replication in a subgroup of HIV-infected long term nonprogressors. Proceedings of the National Academy of Sciences of the United States of America, 2000. 97(6): p. 2709–14.10694578
32 Committee, U.K.C.H.C.S.S., HLA B*5701 status, disease progression, and response to antiretroviral therapy. AIDS, 2013. 27(16): p. 2587–92.23921616
33 Rahmouni, M., L. De Marco, J.L. Spadoni, M. Tison, et al., The HLA-B*57:01 allele corresponds to a very large MHC haploblock likely explaining its massive effect for HIV-1 elite control. Front Immunol, 2023. 14: p. 1305856.38146367
34 Owojuyigbe, T.O., R.A. Bolarinwa, A.S. Adesina, A.A. Ademosun, et al., Human leucocyte antigen B*57.01 allelic gene is uncommon in Nigerians: An implication for antiretroviral therapy among the HIV/AIDS cohort. Indian J Med Res, 2024. 159(5): p. 530–533.39382409
35 Kolou, M., A. Poda, Z. Diallo, E. Konou, et al., Prevalence of human leukocyte antigen HLA-B*57:01 in individuals with HIV in West and Central Africa. BMC Immunol, 2021. 22(1): p. 48.34294032
36 Adechina, A.P., Y.P. Assogba, E. Tchiakpe, and A. Yessoufou, Human leukocyte antigen HLA-B*57:01 status in HIV-1 patients developing hypersensitivity reactions in Benin: a pilot study. BMC Res Notes, 2024. 17(1): p. 208.39075611
37 Masmoudi, H.C., N. Afify, H. Alnaqbi, Z. Alhalwachi, et al., HLA pharmacogenetic markers of drug hypersensitivity from the perspective of the populations of the Greater Middle East. Pharmacogenomics, 2022. 23(12): p. 695–708.35971864
38 Jarrar, Y., N. Hakooz, D.A. Hashem, M. Homsi, et al., Genome-wide screening of pharmacogenomic biomarkers in jordanian patients with genetic disorders. Pharmacogenomics J, 2025. 25(6): p. 28.41109911
39 Dashti, M., M.Z. Malik, A. Al-Matrouk, S. Bhatti, et al., HLA-B allele frequencies and implications for pharmacogenetics in the Kuwaiti population. Front Pharmacol, 2024. 15: p. 1423636.39464636
40 Yilmaz, E., A.F. Kurt, M. Dogruel, D.Y. Sevgi, et al., Frequency of Human Leukocyte Antigen-B*57:01 Allele Carriers in People Living with HIV/AIDS in Turkiye. Curr HIV Res, 2024. 22(4): p. 266–269.39129162
41 Manglani, M.V., Y.R. Gabhale, M.M. Lala, R. Sekhar, et al., HLA- B*5701 Allele in HIV-infected Indian Children and its Association with Abacavir Hypersensitivity. Indian Pediatr, 2018. 55(2): p. 140–141.29242412
42 Kalidasan, V., I. Kunalan, R. Rajasuriar, V.K. Subbiah, et al., HLA-B*57:01 typing in a Malaysian cohort: implications of abacavir hypersensitivity in people living with HIV. Pharmacogenomics, 2023. 24(14): p. 761–769.37767641
43 Yuliwulandari, R., K. Prayuni, K. Viyati, S. Mahasirimongkol, et al., Frequencies of HLA-B alleles in Indonesian Malay Ethnic. Heliyon, 2024. 10(5): p. e26713.38439829
44 Satapornpong, P., P. Jinda, T. Jantararoungtong, N. Koomdee, et al., Genetic Diversity of HLA Class I and Class II Alleles in Thai Populations: Contribution to Genotype-Guided Therapeutics. Front Pharmacol, 2020. 11: p. 78.32180714
45 Koomdee, N., C. Kloypan, P. Jinda, J. Rachanakul, et al., Evolution of HLA-B Pharmacogenomics and the Importance of PGx Data Integration in Health Care System: A 10 Years Retrospective Study in Thailand. Front Pharmacol, 2022. 13: p. 866903.35450046
46 Manson, L.E.N., S.J. Delwig, J.J.M. Drabbels, D.J. Touw, et al., Repurposing HLA genotype data of renal transplant patients to prevent severe drug hypersensitivity reactions. Front Genet, 2023. 14: p. 1289015.37908589
47 Martinez Buitrago, E., J.M. Onate, J.F. Garcia-Goez, J. Alvarez, et al., HLA-B*57:01 allele prevalence in treatment-Naive HIV-infected patients from Colombia. BMC Infect Dis, 2019. 19(1): p. 793.31500584
48 Crovella, S., L. Biller, S. Santos, A. Salustiano, et al., Frequency of HLA B*5701 allele carriers in abacavir treated-HIV infected patients and controls from northeastern Brazil. Clinics (Sao Paulo), 2011. 66(8): p. 1485–8.21915505
49 Echavarria-Correa, S.M., D. Obispo-Achallma, S. Espetia Anco, M.L. Guevara, et al., Distribution of CCR5-Delta32 and HLA-B*57:01 alleles in HIV-seropositive and HIV-exposed seronegative Peruvian individuals. Hum Genome Var, 2025. 12(1): p. 15.40858554
50 Mallal, S., E. Phillips, G. Carosi, J.M. Molina, et al., HLA-B*5701 screening for hypersensitivity to abacavir. N Engl J Med, 2008. 358(6): p. 568–79.18256392
51 Manson, L.E.N., J.J. Swen, and H.J. Guchelaar, Diagnostic Test Criteria for HLA Genotyping to Prevent Drug Hypersensitivity Reactions: A Systematic Review of Actionable HLA Recommendations in CPIC and DPWG Guidelines. Front Pharmacol, 2020. 11: p. 567048.33071783
52 Pavlos, R., P. Deshpande, A. Chopra, S. Leary, et al., New genetic predictors for abacavir tolerance in HLA-B*57:01 positive individuals. Hum Immunol, 2020. 81(6): p. 300–304.32173028
53 Almeida, C.A., A.M. Martin, D. Nolan, A. Lucas, et al., Cytokine profiling in abacavir hypersensitivity patients. Antiviral therapy, 2008. 13(2): p. 281–8.18505179
54 Chessman, D., L. Kostenko, T. Lethborg, A.W. Purcell, et al., Human leukocyte antigen class I-restricted activation of CD8+ T cells provides the immunogenetic basis of a systemic drug hypersensitivity. Immunity, 2008. 28(6): p. 822–32.18549801
55 Lucas, A., M. Lucas, A. Strhyn, N.M. Keane, et al., Abacavir-reactive memory T cells are present in drug naive individuals. PLoS One, 2015. 10(2): p. e0117160.25674793
56 Metushi, I.G., A. Wriston, P. Banerjee, B.O. Gohlke, et al., Acyclovir Has Low but Detectable Influence on HLA-B*57:01 Specificity without Inducing Hypersensitivity. PLoS One, 2015. 10(5): p. e0124878.26024233
57 Ostrov, D.A., B.J. Grant, Y.A. Pompeu, J. Sidney, et al., Drug hypersensitivity caused by alteration of the MHC-presented self-peptide repertoire. Proc Natl Acad Sci U S A, 2012. 109(25): p. 9959–64.22645359
58 Norcross, M.A., S. Luo, L. Lu, M.T. Boyne, et al., Abacavir induces loading of novel self-peptides into HLA-B*57: 01: an autoimmune model for HLA-associated drug hypersensitivity. AIDS, 2012. 26(11): p. F21–9.22617051
59 Illing, P.T., J.P. Vivian, N.L. Dudek, L. Kostenko, et al., Immune self-reactivity triggered by drug-modified HLA-peptide repertoire. Nature, 2012. 486(7404): p. 554–8.22722860
60 White, K., S. Gaudieri, and E. Phillips, HLA and the pharmacogenomics of drug hypersensitivity, in Handbook of Pharmacogenomics and Stratified Medicine. 2014, Elsevier. p. 437–465. Available from.
61 White, K.D., W.H. Chung, S.I. Hung, S. Mallal, et al., Evolving models of the immunopathogenesis of T cell–mediated drug allergy: The role of host, pathogens, and drug response. J. Allergy Clin. Immunol., 2015. 136(2): p. 219–34.26254049
62 Pirmohamed, M., D.A. Ostrov, and B.K. Park, New genetic findings lead the way to a better understanding of fundamental mechanisms of drug hypersensitivity. J Allergy Clin Immunol, 2015. 136(2): p. 236–44.26254050
63 Rodríguez-Nóvoa, S., P. Barreiro, I. Jimenez-Nacher, and V. Soriano, Overview of the pharmacogenetics of HIV therapy. The pharmacogenomics journal, 2006. 6(4): p. 234–45.16462814
64 Cargnin, S., C. Jommi, P.L. Canonico, A.A. Genazzani, et al., Diagnostic accuracy of HLA-B*57:01 screening for the prediction of abacavir hypersensitivity and clinical utility of the test: a meta-analytic review. Pharmacogenomics, 2014. 15(7): p. 963–76.24956250
65 Small, C.B., D.A. Margolis, M.S. Shaefer, and L.L. Ross, HLA-B*57:01 allele prevalence in HIV-infected North American subjects and the impact of allele testing on the incidence of abacavir-associated hypersensitivity reaction in HLA-B*57:01-negative subjects. BMC Infect Dis, 2017. 17(1): p. 256.28399804
66 Ruiz-Iruela, C., N. Padulles-Zamora, D. Podzamczer-Palter, A. Alonso-Pastor, et al., HLA-B*57: 01 genotyping in the prevention of hypersensitivity to abacavir: 5 years of experience. Pharmacogenet Genomics, 2016. 26(8): p. 390–6.27195528
67 Sousa-Pinto, B., C. Correia, L. Gomes, S. Gil-Mata, et al., HLA and Delayed Drug-Induced Hypersensitivity. Int Arch Allergy Immunol, 2016. 170(3): p. 163–79.27576480
68 Michels, A.W. and D.A. Ostrov, New approaches for predicting T cell-mediated drug reactions: A role for inducible and potentially preventable autoimmunity. J Allergy Clin Immunol, 2015. 136(2): p. 252–7.26254052
69 Rai, T.K., J. Chakravarty, K. Priyanka, A. Gautam, et al., Comparison of different methods for the detection of HLA-B* 57:01 allele in people living with HIV in Eastern Uttar Pradesh, India. BMC Infect Dis, 2025. 25(1): p. 1668.41310493
70 Chan, J., G.V. Soraya, L. Craig, S.M. Uddin, et al., Rapid Detection of HLA-B*57:01-Expressing Cells Using a Label-Free Interdigitated Electrode Biosensor Platform for Prevention of Abacavir Hypersensitivity in HIV Treatment. Sensors (Basel), 2019. 19(16).31416185
71 Stainsby, C.M., T.M. Perger, V. Vannappagari, K.C. Mounzer, et al., Abacavir Hypersensitivity Reaction Reporting Rates During a Decade of HLA-B*5701 Screening as a Risk-Mitigation Measure. Pharmacotherapy, 2019. 39(1): p. 40–54.30414209
72 UpToDate. Abacavir hypersensitivity reaction [Cited Feb. 16, 2026]. Available from https://www.uptodate.com/contents/abacavir-hypersensitivity-reaction.
73 Daly, A.K., P.T. Donaldson, P. Bhatnagar, Y. Shen, et al., HLA-B*5701 genotype is a major determinant of drug-induced liver injury due to flucloxacillin. Nat Genet, 2009. 41(7): p. 816–9.19483685
74 Nicoletti, P., G.P. Aithal, T.C. Chamberlain, S. Coulthard, et al., Drug-Induced Liver Injury due to Flucloxacillin: Relevance of Multiple Human Leukocyte Antigen Alleles. Clin Pharmacol Ther, 2019. 106(1): p. 245–253.30661239
75 U.S. FDA. Table of Pharmacogenetic Associations. 2022 10/26/2022 [cited 2026; Available from: https://www.fda.gov/medical-devices/precision-medicine/table-pharmacogenetic-associations#section2.
76 Barker, D.J., R.H.L. Natarajan, M.A. Cooper, S.J.F. Hopper, et al., The IPD-IMGT/HLA database: recent developments in sequence submission. Nucleic Acids Res, 2026. 54(D1): p. D1152–D1158.41251166
77 de Bakker, P.I., G. McVean, P.C. Sabeti, M.M. Miretti, et al., A high-resolution HLA and SNP haplotype map for disease association studies in the extended human MHC. Nature genetics, 2006. 38(10): p. 1166–72.16998491
78 Colombo, S., A. Rauch, M. Rotger, J. Fellay, et al., The HCP5 single-nucleotide polymorphism: a simple screening tool for prediction of hypersensitivity reaction to abacavir. The Journal of infectious diseases, 2008. 198(6): p. 864–7.18684101

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance to nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

^2^ Allele nomenclature for HLA-B*57:01 has been converted to the standardized format. In the cited literature, it may sometimes be written without punctuation (*5701 or *57 01).