# Valproic Acid Therapy and POLG Genotype

## Introduction

Valproic acid (brand name Depakene) is an anti-seizure medication with off-label use in migraine prophylaxis and management of bipolar disorder. It is approved for use in children 2 years of age or older and adults except in the case of pregnancy, hepatic impairment, or known mitochondrial disease due to POLG variation (1). Valproic acid is primarily metabolized in the liver through mitochondrial enzymes or glucuronidation, with a minor route of oxidative metabolism by cytochrome P450 enzymes. It is well established that individuals with POLG-related mitochondrial disease are at significant risk of liver failure and other potentially fatal adverse reactions, leading the US Food and Drug Administration (FDA) list this rare class of disorders as a specific contraindication (Table 1) (1, 2). The drug label also includes a black box warning regarding fetal risk for neural tube defects, decreased IQ, and other major malformations (1). Valproate, sodium valproate, and divalproex are alternate formulations of valproic acid that are processed by the same metabolic pathways and have similar contraindications (3).

Table 1.

FDA Statement Regarding Valproic Acid and POLG-related mitochondrial disease

Condition | Therapeutic recommendation
Known mitochondrial disorder caused by POLG mutation | Valproic acid is contraindicated
Suspected POLG-related disorder in children under 2 years of age | Valproic acid is contraindicated

POLG- mitochondrial DNA polymerase gamma.

Table adapted from (1).

## Drug: Valproic Acid

Valproic acid is used for seizure and epilepsy management but is also used off-label for management of bipolar disorder and migraine prophylaxis (1, 4, 5, 6). In addition to impacting neuronal electrical activity, valproic acid has been noted to function as a histone deacetylase inhibitor (HDACi), which has led to expanded off-label use in adjuvant therapy for multiple conditions including HIV, cancer, and neurodegenerative diseases (4). Valproic acid is one formulation of valproate; additional formulations include sodium valproate and divalproex (an extended-release formulation) (7). Valproic acid and other valproate formulations are not approved by the US Food and Drug Administration (FDA) for use in children under 2 years of age, nor during pregnancy (1, 3). Further, it is not approved for use in individuals with hepatic impairment nor in individuals with known or suspected mitochondrial disease due to POLG genetic variation (1, 4).

Valproic acid is rapidly absorbed from the gastrointestinal tract with 81–89% bioavailability, demonstrates a high affinity for plasma proteins, and has a low volume of distribution—primarily in extracellular fluid (4). The medication crosses the blood-brain barrier where it can achieve the desired anticonvulsive effects as cerebrospinal fluid concentration is typically between 10–20% of plasma concentration (4). Valproic acid can also cross the placenta, and fetal concentrations reach 70–100% of maternal concentrations. Valproic acid is primarily metabolized in the liver, though other tissues also express many of the enzymes involved in its metabolism (1, 6).

The primary route of valproic acid metabolism is via glucuronidation by UGT enzymes to form inactive metabolites (4). It is also beta-oxidized in the tricarboxylic acid cycle (TCA) within mitochondria, with oxidation by cytochrome P450 enzymes playing only a minor contribution to valproic acid metabolism (4). Less than 3% of valproic acid is excreted unchanged (1). Urinary excretion is the primary route of elimination for valproic acid and its metabolites (4). The therapeutic range in serum is 50–100 mcg/mL (4, 6).

The mechanism of action for valproic acid is not fully understood, but there are several suggested mechanisms in the literature (4). It may act directly on voltage-gated sodium channels, reducing their activity and thus decreasing the frequency of spurious neuron firing. Valproic acid impacts gamma-aminobutyric acid (GABA) levels by both indirectly inhibiting GABA transaminase (6) and promoting GABA synthesis via glutamic acid decarboxylase expression and activity (8). Further evidence indicates that valproic acid modulates the activity of calcium channels and inhibits histone deacetylase (particularly isoform 1), leading to increased histone acetylation and more open chromatin structure, which in turn increases expression of genes (4).

Valproic acid therapy can cause a range of side effects. Common but shorter-term reactions include gastrointestinal, neurologic, and hematologic adverse effects such as headache, dizziness, somnolence, abdominal pain, nausea and vomiting, diarrhea, and thrombocytopenia (4). More severe, but less frequent reactions have been reported that can affect nearly any organ system. These serious adverse reactions include hepatotoxicity that can lead to liver failure, birth defects, pancreatitis, hallucinations, suicidality, skin reactions such as toxic epidermal necrolysis or Stevens-Johnson syndrome, erythema multiforme, anaphylaxis, hyponatremia, hypothermia, cerebral pseudoatrophy, and coma (1, 4). Bleeding and hematopoietic disorders like thrombocytopenia, pancytopenia, myelosuppression, and aplastic anemia have also been reported (1). Hyperammonemia is also possible with valproic acid and can lead to encephalopathy or reversible cognitive decline which may be misdiagnosed as dementia (4, 9). Pediatric cases of valproic acid-induced Fanconi syndrome have also been reported (10). Both valproic acid and its metabolites have been implicated as the toxic drivers for these adverse events (6, 7). Some evidence suggests that L-carnitine can mitigate symptoms of valproic acid induced hyperammonemia and hepatotoxicity (11).

Due to the critical contribution of the liver in metabolizing valproic acid, individuals with hepatic disease or significant hepatic dysfunction are contraindicated from taking valproic acid (1). Serum liver testing is recommended prior to therapy and at frequent intervals following valproate initiation, as hepatic failure usually occurs in the first 6 months of treatment (1). Individuals with known urea cycle disorders should not use valproic acid, as they are at increased risk of developing hyperammonemic encephalopathy (1). Acute pancreatitis has been reported in both children and adults in response to valproic acid therapy (1, 12, 13). Pancreatitis can occur at any time during therapy and can be fatal; signs and symptoms include abdominal pain, nausea, vomiting, anorexia or a combination of these symptoms (1, 13). Pancreatitis is an indication to discontinue valproic acid in favor of an alternate medication (1).

Valproic acid is contraindicated during pregnancy due to the high risk to the fetus and potential adverse effects to the mother. Multiple birth defects including spina bifida, cardiac septal defects, oral clefts, and adverse neurodevelopmental outcomes have been linked to valproate use during pregnancy (1, 14). Indeed, epidemiologic studies suggest that in utero exposure to valproic acid correlates with lower IQ scores and a risk of neurodevelopmental disorders as compared to either no medication exposure or other anti-epileptic drugs, with reports indicating 30–40% of children with prenatal valproic acid exposure have problems with early childhood development (1, 15). Further, studies have estimated that exposure to antiseizure medications, like valproic acid, in the 60 days prior to birth are associated with a 29% increased risk of neurodevelopmental disorders (16). Another study reported a hazard ratio of 2.67 with valproate use during pregnancy and the child receiving a diagnosis of autism spectrum disorder (17). While there is some indication that severe birth defect risk is directly correlated with dosing, there is no established threshold for a tolerated, safe dose during pregnancy (1). Additionally, women taking valproic acid may experience adverse effects such as hematologic abnormalities that are a risk to both mother and neonate (1). Even if the mother does not develop hepatoxicity, there have been cases of infantile hepatic failure following in utero exposure to valproate (1).

These risks should be weighed against the risks of discontinuing valproic acid or switching to other medications given that ceasing anti-epileptic therapy could trigger a maternal seizure which bears its own risks to both mother and fetus (1). Indications like migraine prevention or treatment of mood disorders, are a common source (22–40%) of prenatal exposure to valproic acid, with epilepsy management being less frequently reported as the associated maternal indication (14%) (18). Following regulatory guidance changes in the United Kingdom in 2018, the use of valproic acid in women of childbearing potential decreased between 2019 and 2023 across all age groups analyzed (19).

Levels of valproic acid in breast milk are low to undetectable, and current data provide no indication of a significant safety risk to breastfed infants (20). The level of valproate in human milk corresponds to 1-10% of maternal serum levels (1). There is a very low risk of hepatotoxicity or thrombocytopenia in the breast fed infant following valproic acid use by the mother. Mothers and pediatricians are encouraged to monitor the infant for jaundice, bleeding, or bruising. There are additional risks of sedation, or withdrawal may arise if the mother uses a combination therapy with a sedative anticonvulsant medication. The LactMed resource provides a list of alternate drugs that can be considered based on the indicated condition (20).

Children under 2 years of age should not be prescribed valproic acid due to their considerably increased risk of hepatotoxicity (1). Above 2 years of age, the risk of fatal hepatoxicity decreases with increasing age, however it should be noted that individuals between the ages of 3 months and 10 years have 50% higher clearance rates based on weight as compared to adults and may require higher doses to achieve therapeutic plasma concentrations (1). There are reports of children developing cerebral and cerebellar pseudoatrophy following valproic acid therapy, which may be reversible upon medication withdrawal (21, 22, 23, 24, 25, 26).

Individuals of advanced age (65 years or older) reported a higher frequency of accidental injury, infection, pain, somnolence, and tremor than adults below 65 years of age (1). Somnolence was particularly frequent in individuals with dementia and was a common cause of medication discontinuation. Dosing for these individuals should be initiated at lower levels than younger adult doses (1). There is evidence that valproic acid for management of psychiatric symptoms among residents of nursing homes has increased in recent years, but the safety and efficacy of this medication compared to others remains unclear for this population (27). The use of valproic acid to manage post-stroke epilepsy has been associated with higher risk of seizure recurrence (28). Studies of prescribing trends for adults in the US and Germany suggest that valproic acid is prescribed in 5–10% of adults aged 65 years and older who require antiseizure medication (29, 30).

## Gene: POLG

The POLG gene (located on nuclear chromosome 15q26, sometimes called POLG1) encodes the alpha subunit of the mitochondrial DNA polymerase gamma enzyme. This is the catalytic subunit of the DNA polymerase that drives mitochondrial DNA replication and is responsible for the proofreading activity of the complex (31, 32, 33). Mitochondria are cellular organelles that produce energy in the form of ATP via oxidative phosphorylation. Mitochondria require both nuclear and mitochondrial encoded gene products to form the respiratory chain complexes. Cells contain hundreds to thousands of mitochondria, and each mitochondrion contains multiple copies of the mitochondrial genome. Dysfunctional DNA polymerase gamma can cause depletion of mitochondrial DNA as well as accumulation of pathogenic variants or deletions in the mitochondrial genome (33). Without sufficient DNA content in mitochondria, respiratory chain components are depleted, and the organelle cannot generate sufficient cellular energy, leading to cell death (34).

Variation in POLG has been implicated in a spectrum of genetic disorders which can variably affect the neurologic, gastrointestinal, ophthalmic, auditory, neuromuscular, endocrine, renal and respiratory systems (2). There is a correlation between the severity of phenotype and age of onset, with the earliest onset conditions being the most severe and often accompanied by mitochondrial DNA depletion (2, 35). Epilepsy is present in approximately 70% of individuals with POLG-related disorders, which occur at a global estimated frequency of 1 in 10,000 worldwide (2). Most but not all POLG-disorders are inherited in an autosomal recessive pattern, and the most common pathogenic DNA variants are NM_002693.3:c.1399G>A (NP_002684.1:p.Ala467Thr), c.2243G > C (p. Trp748Ser), c.2542G>A (p.Gly848Ser) and linked variants p.[Thr251Ile;Pro587Leu] (2). There are many more variants that are less frequently observed. In fact, over 267 pathogenic variants have been reported in ClinVar and approximately 300 clinically relevant variants are cited in the medical literature (33, 35, 36).

Other genes of interest: CYP2C9, CYP2D6, CYP2C19, UGT1A6, UGT1A9, UGT2B7

The Cytochrome P450 (CYP) Family

The cytochrome P450 proteins are crucial metabolizing enzymes for a wide range of substances, including medications, potentially toxic compounds, hormones, and fat-soluble vitamins (37). Generally, CYP enzymes are classified as monooxygenases and contribute to either the activation of prodrugs or the inactivation of drugs to promote their excretion from the body (depending on the specific CYP enzyme and medications) (37). The genes encoding the CYP enzymes are encoded across multiple autosomal chromosomes and are highly polymorphic. Many variants in the CYP genes alter the protein activity or expression level of the mRNA, leading to interpersonal variation in CYP enzyme activity. Individuals can be classified as poor, intermediate, normal, rapid, or ultrarapid metabolizers for the CYP2D6, CYP2C19, and CYP2C9 genes (38, 39, 40). The CYP proteins are highly expressed in the liver but are also robustly expressed in the intestines and kidneys (37). The CYP enzymes are responsible for phase I of drug metabolism which includes oxidation, reduction, and hydrolysis (37). Less than 15-20% of valproic acid is metabolized by CYP enzymes (1).

The Uridine Diphosphate Glucuronosyltransferase (UGT) Family

The UGT (uridine diphosphate-glucuronosyltransferase) enzymes are a superfamily of proteins that metabolize a wide range of lipophilic molecules, including bilirubin, steroids, toxins, and drugs. These enzymes mediate glucuronidation, a phase II metabolic pathway in which glucuronic acid is conjugated to specific targets to convert them into water-soluble metabolites that can then be eliminated from the body (41, 42). The UGT family of proteins is primarily expressed in the liver, but is also present in the intestines, stomach and breast tissues (41).

The UGT genes are polymorphic, and genomic processes such as variant splicing and epigenetic factors likely contribute to their diversity. As a result, the substrates catalyzed by UGT enzymes are particularly variable (43). In humans, the UGT superfamily has 22 enzymes divided into 4 families, of which UGT1A and UGT2B are members (44). Genetic variation can lead to differences in UGT enzyme activity between individuals (43), though exogenous compounds can also inhibit the UGT enzymatic activity. Alternative splicing at the UGT loci produces multiple isoforms (for example, UGT1A1 and UGT1A3) (45, 46).

Phenoconversion with Valproic acid

Valproic acid is a substrate and inhibitor of multiple UGT isoforms, including UGT1A4 and UGT2B7, as well as CYP2C9 and other CYP isoforms (47). Conversely, it may interact with substrates of these same enzymes such as lamotrigine, carbamazepine, phenytoin, phenobarbital or primidone potentially resulting in decreased metabolism of one of the antiepileptic medications when taken concomitantly (1, 47). Notably, the FDA approved labeling states that lamotrigine dosage should be reduced when co-administered with valproic acid due to the potential for serious skin reactions such as Stevens-Johnson syndrome and toxic epidermal necrolysis (1). Physiologically based pharmacokinetic models have been developed for valproic acid drug-drug interactions, but not a genomic deficiency of UGT or CYP activity (47, 48). Additionally, valproic acid has been shown to impact vixotrigine metabolism via UGT inhibition (49). The HDACi activity of valproic acid therapy may also trigger upregulation of metabolizing enzymes, such as UGT1A6, that can affect the metabolism of other UGT substrate medications (50).

## Linking POLG Genetic Variation with Treatment Response

Hepatotoxicity is a known adverse effect of valproic acid and this risk is increased in individuals with POLG loss of function alleles (51). The mitochondria are a key organelle in valproic acid metabolism. Toxic valproic acid metabolites are formed in the mitochondria and can cause excessive stress via increased reactive oxygen species, decreased free Coenzyme A levels, and depletion of mitochondrial DNA and carnitine (6, 52, 53, 54). Thus, despite HDACi activity of valproic acid triggering an upregulation of genes involved in mitochondrial proliferation, POLG deficient mitochondria appear unable to withstand the stress of valproic acid administration (55).

Individuals with POLG variants have experienced a range of clinical adverse events in response to valproic acid therapy. Genetic variation in POLG is strongly associated with liver toxicity due to valproic acid therapy (odds ratio 23.6) (56) and has resulted in liver failure requiring transplantation even amongst children (57). Individuals of any age can develop liver toxicity in response to valproic acid (58). A young adult with seizures experienced liver failure requiring a transplant after 3 months of valproic acid therapy whereby biallelic POLG variants were discovered after initiation of valproic acid therapy (59). Another study reported 5 individuals with valproate-induced liver failure and POLG biallelic variants, ultimately concluding that POLG molecular analysis should be performed in all individuals with suspected mitochondrial disease prior to initiating valproic acid therapy (60). Additionally, there have been case reports of pediatric fatalities following valproic acid therapy for seizures, in both known and unknown POLG variant carriers (61, 62). In some cases, individuals have recovered liver function following withdrawal of valproic acid (63).

Other mitochondrial diseases:

Limited data from the literature suggests individuals with mitochondrial diseases unrelated to POLG variation may also experience toxicity due to valproic acid therapy (64, 65, 66). Historically, some authors have discouraged use of valproic acid in individuals with known mitochondrial disorders, regardless of the underlying molecular etiology (67, 68, 69). However, more recent consensus-based statements affirm that individuals with normal liver function and mitochondrial disease not due to POLG variation can be treated with valproic acid to manage refractory epilepsy or mood disorders (70). Similarly, others have recommended use of valproic acid therapy for intractable status epilepticus in mitochondrial diseases not due to POLG variation (71). Additional analysis has concluded that individuals with non-POLG mitochondrial disease have a limited risk of adverse effects with valproic acid therapy, particularly compared to the well documented, high risk for POLG-related mitochondrial disease (72).

Several case reports have indicated neurological atrophy following valproic acid therapy in individuals, some of whom were subsequently found to have mitochondrial DNA variations (though many cases reported no mitochondrial sequencing results) (23, 24, 26, 73, 74, 75). Underlying mitochondrial disease amplifies the risk of hepatotoxicity and mortality with valproic acid therapy (4).

In the context of valproic acid use for bipolar disorder, one study reported that a mitochondrial DNA copy number (MCN) of 2.05 or above correlated with a positive response to therapy as compared to lower MCN (76). The study authors hypothesize that valproic acid therapy enhances mitochondrial function and thus the increased MCN indicates a beneficial effect (76). Indeed, there is evidence that valproic acid and its metabolites can have both beneficial and toxic effects on mitochondria, but the balance of these effects may skew toward toxicity when there is an underlying disturbance in drug metabolic pathways, including beta oxidation in mitochondria (6).

Potential contribution of CYP and UGT Enzymes to Treatment Response

Given the importance of CYP- and UGT-mediated valproic acid metabolism, many research groups have investigated the correlation of genetic variation at these loci to the efficacy or rate of side effects associated with valproic acid therapy. Amongst the published studies, there is little agreement on the clinical significance of any single CYP or UGT gene in predicting individual variation in response to valproic acid. Thus, no actionable guidelines exist at the time of writing with respect to genotype informed dosing.

Variants at the CYP2C9 and CYP2A6 loci have shown some impact on valproic acid plasma levels, with CYP2C9*3 (rs1057910, NM_000771.4:c.1075A>C: a loss of function allele) and CYP2A6*4 (a structural allele leading to loss of function) correlating with higher plasma levels (77). The association with increased plasma levels and CYP2C9*3 has been replicated in at least one other study (78). CYP2D6*4 (rs3892097, NM_000106.6:c.506-1G>A, a loss of function allele) has been associated with 2.5 times higher risk of treatment failure with valproic acid for genetic generalized epilepsies (78). Another study reported higher plasma levels (concentration to dose ratio) in individuals heterozygous for CYP2C19*2 (rs4244285, NM_000769.4:c.681G>A: a loss of function allele) (79). The clinical significance of these changes in plasma levels remain to be demonstrated, but the impact may be low, owing to the relatively small contribution of CYPs to valproic acid metabolism.

The UGT enzymes, however, account for a more substantial pathway in valproic acid metabolism. The observed effect of genetic variation at UGT1A6 on valproic acid metabolism has varied across studies. Individuals with the variant allele at NM_001072.4:c.552A>C (rs1105879) or NM_001072.4:c.541A>G (rs2070959) were observed to have a lower plasma concentration as compared to homozygous reference allele individuals (80), though other groups reported no significant differences based on these genotypes (81, 82). One study reported an association between NM_001072.4:c.541A>G variation and an increased risk of tremor with valproic acid therapy (83).

Additional studies have examined variation at UGT1A6, UGT2B7, UGT1A8 as contributing factors to valproic acid metabolism and response, highlighting the need for robust replication of the reported findings to determine if these loci have clinical impact (78, 83, 84, 85). The ancestral background and frequency of variant alleles within the study cohorts, age of study participants, and other factors may also contribute to differences in association between these loci among the reports.

One population based pharmacokinetic model incorporated genetic variation at multiple loci, specifically UGT1A8 (rs1042597, NM_019076.4:c.518C>G), UGT2B7 (rs28365062, NM_001074.2:c.735A>G), and CYP2C19 (rs4986893, NM_000769.4:c.636G>A, and rs4244285) as significantly influencing VPA clearance in a cohort of 290 children treated in a Beijing hospital (86). This model also included total daily dose and body surface area as predictors of individual variability in valproic acid clearance, highlighting the complexity of valproic acid metabolism and therapeutic management (86).

## Genetic Testing

The NIH Genetic Testing Registry (GTR®) provides a listing of tests for valproic acid response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN078027) and POLG (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=5428%5bgeneid%5d) genotype. The FDA states that valproic acid therapy is contraindicated for individuals with known mitochondrial disease due to POLG pathogenic variation, but does not require testing before initiating therapy (1). Recommendations for diagnostic testing of mitochondrial disease have been issued by the Mitochondrial Medicine Society, covering both biochemical testing and DNA-based testing (87).

If DNA-based testing is utilized for a primary mitochondrial disease diagnosis, the source of the DNA sample should be carefully considered. Mitochondrial DNA (mtDNA) exists in many copies per cell, and not all mitochondrial genomes have the same genotype, even within a single cell (called heteroplasmy). Additionally, the distribution of mitochondrial genotypes can vary between tissues, and the affected tissues may have a higher mutational burden in mtDNA than whole blood. Urine may also be a viable sample type, as renal epithelial cells have high mtDNA content (87). Mitochondria-specific tests (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=mitochondria) available in GTR may cover mtDNA, nuclear DNA, or both.

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA):

Patients with Mitochondrial Disease: There is an increased risk of valproate-induced acute liver failure and resultant deaths in patients with hereditary neurometabolic syndromes caused by DNA mutations of the mitochondrial DNA Polymerase (POLG) gene (e.g. Alpers Huttenlocher Syndrome). Valproic Acid … [is] contraindicated in patients known to have mitochondrial disorders caused by POLG mutations and children under two years of age who are clinically suspected of having a mitochondrial disorder. In patients over two years of age who are clinically suspected of having a hereditary mitochondrial disease, Valproic Acid … should only be used after other anticonvulsants have failed. This older group of patients should be closely monitored during treatment with Valproic Acid … for the development of acute liver injury with regular clinical assessments and serum liver testing. POLG mutation screening should be performed in accordance with current clinical practice. The A467T and W748S mutations are present in approximately 2/3 of patients with autosomal recessive POLG-related disorders.

Please review the complete therapeutic recommendations that are located here: (1)

## Nomenclature for selected POLG alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
A467T | c.1399G > A (p.Ala467Thr) | NM_002693.3:c.1399G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/13496/) | NP_002684.1:p.Ala467Thr | rs113994095 (https://www.ncbi.nlm.nih.gov/snp/rs113994095)
W748S | c.2243G > C (p. Trp748Ser) | NM_002693.3:c.2243G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/13507/) | NP_002684.1:p.Trp748Ser | rs113994097 (https://www.ncbi.nlm.nih.gov/snp/rs113994097)
G848S | c.2542G > A (p.Gly848Ser) | NM_002693.3:c.2542G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/13502/) | NP_002684.1:p.Gly848Ser | rs113994098 (https://www.ncbi.nlm.nih.gov/snp/rs113994098)
(None) | p.[Thr251Ile;Pro587Leu] | NM_002693.3:c.[1760C>T;752C>T] (https://www.ncbi.nlm.nih.gov/clinvar/variation/1698500/) | NP_002684.1:p.[Thr251Ile; Pro587Leu] | rs113994094 (https://www.ncbi.nlm.nih.gov/snp/rs113994094) rs113994096 (https://www.ncbi.nlm.nih.gov/snp/rs113994096)

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

## Acknowledgments

The author would like to thank Michelangelo Mancuso, MD, PhD, Professor of Clinical and Experimental Medicine, Neurological Institute, University of Pisa, Pisa, Italy and Nathalie K. Zgheib, MD, Professor, Pharmacology and Toxicology, American University of Beirut, Faculty of Medicine, Beirut, Lebanon for providing an expert review of this summary.

## References

1. VALPROIC ACID capsule, liquid filled. Bionpharma Inc.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=ceb52870-76d0-4108-a1d4-ba7096fbacdd.

2. Cohen, B.H., P.F. Chinnery, and W.C. Copeland, POLG-Related Disorders, in GeneReviews((R)), M.P. Adam, et al., Editors. 1993: Seattle (WA). Available from https://www.ncbi.nlm.nih.gov/pubmed/20301791.

3. US Food and Drug Administration. FDA Drug Safety Communication: Valproate Anti-seizure Products Contraindicated for Migraine Prevention in Pregnant Women due to Decreased IQ Scores in Exposed Children. 2013; Available from: https://wayback.archive-it.org/7993/20170113093202/http:/www.fda.gov/downloads/Drugs/DrugSafety/UCM350748.pdf.

4. Rahman, M., A.O. Awosika, and H. Nguyen, Valproic Acid, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/32644538.

5. Mari, J., L.H.J. Dieckmann, D. Prates-Baldez, M. Haddad, et al., The efficacy of valproate in acute mania, bipolar depression and maintenance therapy for bipolar disorder: an overview of systematic reviews with meta-analyses. BMJ Open, 2024. 14(11): p. e087999.

6. Shnayder, N.A., V.V. Grechkina, A.K. Khasanova, E.N. Bochanova, et al., Therapeutic and Toxic Effects of Valproic Acid Metabolites. Metabolites, 2023. 13(1).

7. Patel, A.R. and S. Nagalli, Valproate Toxicity, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/32809733.

8. Gavin, D.P., S. Kartan, K. Chase, S. Jayaraman, et al., Histone deacetylase inhibitors and candidate gene expression: An in vivo and in vitro approach to studying chromatin remodeling in a clinical population. J Psychiatr Res, 2009. 43(9): p. 870–6.

9. Alsukhni, R.A., J. Johnson, and L. Nashef, Valproate-induced reversible cognitive decline presenting as dementia and associated clinical features: A literature review. Seizure, 2023. 111: p. 45–50.

10. Sawamura, F., J. Natsume, Y. Ito, T. Mitsumatsu, et al., Latent renal tubular dysfunction in patients with epilepsy treated with valproic acid. Epilepsy Res, 2025. 216: p. 107611.

11. Gziut, T. and R. Thanacoody, L-carnitine for valproic acid-induced toxicity. Br J Clin Pharmacol, 2025. 91(3): p. 636–647.

12. Cofini, M., F. Quadrozzi, P. Favoriti, M. Favoriti, et al., Valproic acid-induced acute pancreatitis in pediatric age: case series and review of literature. G Chir, 2015. 36(4): p. 158–60.

13. Bischof, M.C.M., M.I.E. Stadelmann, S. Janett, M.G. Bianchetti, et al., Valproic Acid-Associated Acute Pancreatitis: Systematic Literature Review. J Clin Med, 2023. 12(18).

14. Winterstein, A.G., Risk Management of Valproate and Other Teratogenic Anticonvulsants in the Era of Proliferating Use. J Pediatr Pharmacol Ther, 2025. 30(3): p. 398–400.

15. Valproate – reproductive risks. 2025 23 Sept 2025 7 Jan 2026]; Available from: https://www.gov.uk/guidance/valproate-reproductive-risks.

16. Sheehy, O., V. Tchuente, S. Eltonsy, S. Hawken, et al., Late Pregnancy Antiseizure Medication Exposure and Offspring Neurodevelopmental Risk: A Multi-Child Cohort Study. Ann Neurol, 2025.

17. Hernandez-Diaz, S., L. Straub, B.T. Bateman, Y. Zhu, et al., Risk of Autism after Prenatal Topiramate, Valproate, or Lamotrigine Exposure. N Engl J Med, 2024. 390(12): p. 1069–1079.

18. Smolinski, N.E., A. Sarayani, T.N. Thai, S. Jugl, et al., Prenatal Exposure to Valproic Acid Across Various Indications for Use. JAMA Netw Open, 2024. 7(5): p. e2412680.

19. Dale, C.E., R. Takhar, Y.Y. Fan, F. Torabi, et al., Use of sodium valproate and other antiseizure drug treatments in England and Wales: quantitative analysis of nationwide linked electronic health records. BMJ Med, 2024. 3(1): p. e000760.

20. Valproic Acid, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000333.

21. Ordono-Saiz, M.V., R.C. Pua-Torrejon, M. Justel-Rodriguez, E. Arias-Vivas, et al., Cerebral and cerebellar pseudoatrophy associated with valproic acid. Report of three pediatric cases. Rev Neurol, 2023. 77(8): p. 197–201.

22. Umlauf, J., A. Rau, T. Demerath, T. Bast, et al., Valproate associated brain volume-loss in pediatric epilepsy-A case series. Epilepsia Open, 2023. 8(4): p. 1581–1587.

23. Lovett, M., D.L. Skidmore, and I.S. Mohamed, Valproate-induced pseudoatrophy: expanding the clinical and imaging spectrum. Pediatr Neurol, 2014. 51(2): p. 284–5.

24. Galimberti, C.A., M. Diegoli, I. Sartori, C. Uggetti, et al., Brain pseudoatrophy and mental regression on valproate and a mitochondrial DNA mutation. Neurology, 2006. 67(9): p. 1715–7.

25. McLachlan, R.S., Pseudoatrophy of the brain with valproic acid monotherapy. Can J Neurol Sci, 1987. 14(3): p. 294–6.

26. Guerrini, R., A. Belmonte, R. Canapicchi, C. Casalini, et al., Reversible pseudoatrophy of the brain and mental deterioration associated with valproate treatment. Epilepsia, 1998. 39(1): p. 27–32.

27. Winter, J.D., J.W. Kerns, D.M. Qato, L. Wastila, et al., A National Survey of Nursing Home Clinicians to Explain Increased Valproate Prescribing. Am J Geriatr Psychiatry, 2025. 33(11): p. 1197–1206.

28. Ouerdiene, A., M. Messelmani, H. Derbali, M. Mansour, et al., Post-stroke seizures: risk factors and management after ischemic stroke. Acta Neurol Belg, 2023. 123(1): p. 145–152.

29. Hochbaum, M., R. Kienitz, F. Rosenow, J. Schulz, et al., Trends in antiseizure medication prescription patterns among all adults, women, and older adults with epilepsy: A German longitudinal analysis from 2008 to 2020. Epilepsy Behav, 2022. 130: p. 108666.

30. Terman, S.W., B.E. Youngerman, H. Choi, and J.F. Burke, Antiseizure medication treatment pathways for US Medicare beneficiaries with newly treated epilepsy. Epilepsia, 2022. 63(6): p. 1571–1579.

31. NCBI Datasets, Gene. POLG- DNA polymerase gamma, catalytic subunit [Cited Aug 14, 2025]. Available from https://www.ncbi.nlm.nih.gov/datasets/gene/5428/.

32. O'Leary, N.A., E. Cox, J.B. Holmes, W.R. Anderson, et al., Exploring and retrieving sequence and metadata for species across the tree of life with NCBI Datasets. Sci Data, 2024. 11(1): p. 732.

33. Young, M.J. and W.C. Copeland, Human mitochondrial DNA replication machinery and disease. Curr Opin Genet Dev, 2016. 38: p. 52–62.

34. Hikmat, O., T. Eichele, C. Tzoulis, and L.A. Bindoff, Understanding the Epilepsy in POLG Related Disease. Int J Mol Sci, 2017. 18(9).

35. Nicholas Russo, S., E.G. Shah, W.C. Copeland, and M.K. Koenig, A new pathogenic POLG variant. Mol Genet Metab Rep, 2022. 32: p. 100890.

36. ClinVar. ClinVar, "POLG"[GENE] [Cited Aug 15, 2025]. Available from https://www.ncbi.nlm.nih.gov/clinvar.

37. Gilani, B. and M. Cassagnol, Biochemistry, Cytochrome P450, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/32491630.

38. Scott, S.A., K. Sangkuhl, A.R. Shuldiner, J.S. Hulot, et al., PharmGKB summary: very important pharmacogene information for cytochrome P450, family 2, subfamily C, polypeptide 19. Pharmacogenet Genomics, 2012. 22(2): p. 159–65.

39. Owen, R.P., K. Sangkuhl, T.E. Klein, and R.B. Altman, Cytochrome P450 2D6. Pharmacogenet Genomics, 2009. 19(7): p. 559–62.

40. Van Booven, D., S. Marsh, H. McLeod, M.W. Carrillo, et al., Cytochrome P450 2C9-CYP2C9. Pharmacogenet Genomics, 2010. 20(4): p. 277–81.

41. Barbarino, J.M., C.E. Haidar, T.E. Klein, and R.B. Altman, PharmGKB summary: very important pharmacogene information for UGT1A1. Pharmacogenet Genomics, 2014. 24(3): p. 177–83.

42. Steventon, G., Uridine diphosphate glucuronosyltransferase 1A1. Xenobiotica, 2020. 50(1): p. 64–76.

43. Meech, R., D.G. Hu, R.A. McKinnon, S.N. Mubarokah, et al., The UDP-Glycosyltransferase (UGT) Superfamily: New Members, New Functions, and Novel Paradigms. Physiol Rev, 2019. 99(2): p. 1153–1222.

44. Mackenzie, P.I., K.W. Bock, B. Burchell, C. Guillemette, et al., Nomenclature update for the mammalian UDP glycosyltransferase (UGT) gene superfamily. Pharmacogenet Genomics, 2005. 15(10): p. 677–85.

45. van Es, H.H., A. Bout, J. Liu, L. Anderson, et al., Assignment of the human UDP glucuronosyltransferase gene (UGT1A1) to chromosome region 2q37. Cytogenet Cell Genet, 1993. 63(2): p. 114–6.

46. Sissung, T.M.B., R., L.M. Cordes, and W.G. Figg, UGT1A1 Polymorphisms and Mutations Affect Anticancer Drug Therapy, in Handbook of Therapeutic Biomarkers in Cancer, S.X.D. Yang, J.E., Editor. 2021, Jenny Stanford Publishing: New York, NY.

47. Conner, T.M., V.C. Nikolian, P.E. Georgoff, M.P. Pai, et al., Physiologically based pharmacokinetic modeling of disposition and drug-drug interactions for valproic acid and divalproex. Eur J Pharm Sci, 2018. 111: p. 465–481.

48. Xu, S., L. Liu, Y. Chen, M. Liu, et al., Population pharmacokinetics of lamotrigine co-administered with valproic acid in Chinese epileptic children using nonlinear mixed effects modeling. Eur J Clin Pharmacol, 2018. 74(5): p. 583–591.

49. Zhao, Y., M. Kotecha, H. Finnigan, M. Serenko, et al., Evaluation of the Effect of Uridine Diphosphate-Glucuronosyltransferases (UGT) Inhibition by Valproic Acid on Vixotrigine Pharmacokinetics in Healthy Volunteers. Clin Drug Investig, 2022. 42(10): p. 829–837.

50. Sakakibara, Y., A. Kojima, Y. Asai, M. Nadai, et al., Changes in uridine 5'-diphospho-glucuronosyltransferase 1A6 expression by histone deacetylase inhibitor valproic acid. Biopharm Drug Dispos, 2022. 43(5): p. 175–182.

51. Ghodke-Puranik, Y., C.F. Thorn, J.K. Lamba, J.S. Leeder, et al., Valproic acid pathway: pharmacokinetics and pharmacodynamics. Pharmacogenet Genomics, 2013. 23(4): p. 236–41.

52. Schumacher, J.D. and G.L. Guo, Mechanistic review of drug-induced steatohepatitis. Toxicol Appl Pharmacol, 2015. 289(1): p. 40–7.

53. Grunig, D., L. Szabo, M. Marbet, and S. Krahenbuhl, Valproic acid affects fatty acid and triglyceride metabolism in HepaRG cells exposed to fatty acids by different mechanisms. Biochem Pharmacol, 2020. 177: p. 113860.

54. Finsterer, J., Toxicity of Antiepileptic Drugs to Mitochondria. Handb Exp Pharmacol, 2017. 240: p. 473–488.

55. Sitarz, K.S., H.R. Elliott, B.S. Karaman, C. Relton, et al., Valproic acid triggers increased mitochondrial biogenesis in POLG-deficient fibroblasts. Mol Genet Metab, 2014. 112(1): p. 57–63.

56. Stewart, J.D., R. Horvath, E. Baruffini, I. Ferrero, et al., Polymerase gamma gene POLG determines the risk of sodium valproate-induced liver toxicity. Hepatology, 2010. 52(5): p. 1791–6.

57. Mindikoglu, A.L., D. King, L.S. Magder, J.A. Ozolek, et al., Valproic acid-associated acute liver failure in children: case report and analysis of liver transplantation outcomes in the United States. J Pediatr, 2011. 158(5): p. 802–7.

58. Saneto, R.P., I.C. Lee, M.K. Koenig, X. Bao, et al., POLG DNA testing as an emerging standard of care before instituting valproic acid therapy for pediatric seizure disorders. Seizure, 2010. 19(3): p. 140–6.

59. Bassett, J.T., B. Rodriguez, L. Mulligan, and R.J. Fontana, Acute liver failure in a military recruit treated with valproic acid and harboring a previously unrecognized POLG-1 mutation. Epilepsy Behav Rep, 2019. 12: p. 100342.

60. Hynynen, J., T. Komulainen, E. Tukiainen, A. Nordin, et al., Acute liver failure after valproate exposure in patients with POLG1 mutations and the prognosis after liver transplantation. Liver Transpl, 2014. 20(11): p. 1402–12.

61. Tarka, S., M. Laure-Kamionowska, T. Wierzba-Bobrowicz, K. Witulska, et al., POLG gene mutation. Clinico-neuropathological study. Folia Neuropathol, 2020. 58(4): p. 386–392.

62. Pronicka, E., A. Weglewska-Jurkiewicz, M. Pronicki, J. Sykut-Cegielska, et al., Drug-resistant epilepsia and fulminant valproate liver toxicity. Alpers-Huttenlocher syndrome in two children confirmed post mortem by identification of p.W748S mutation in POLG gene. Med Sci Monit, 2011. 17(4): p. CR203–9.

63. McFarland, R., G. Hudson, R.W. Taylor, S.H. Green, et al., Reversible valproate hepatotoxicity due to mutations in mitochondrial DNA polymerase gamma (POLG1). Arch Dis Child, 2008. 93(2): p. 151–3.

64. Lin, C.M. and P. Thajeb, Valproic acid aggravates epilepsy due to MELAS in a patient with an A3243G mutation of mitochondrial DNA. Metab Brain Dis, 2007. 22(1): p. 105–9.

65. Lam, C.W., C.H. Lau, J.C. Williams, Y.W. Chan, et al., Mitochondrial myopathy, encephalopathy, lactic acidosis and stroke-like episodes (MELAS) triggered by valproate therapy. Eur J Pediatr, 1997. 156(7): p. 562–4.

66. Vantroys, E., J. Smet, A.V. Vanlander, S. Vergult, et al., Severe hepatopathy and neurological deterioration after start of valproate treatment in a 6-year-old child with mitochondrial tryptophanyl-tRNA synthetase deficiency. Orphanet J Rare Dis, 2018. 13(1): p. 80.

67. Finsterer, J. and S. Zarrouk-Mahjoub, Management of epilepsy in MERRF syndrome. Seizure, 2017. 50: p. 166–170.

68. Paiva Coelho, M., E. Martins, and L. Vilarinho, Diagnosis, management, and follow-up of mitochondrial disorders in childhood: a personalized medicine in the new era of genome sequence. Eur J Pediatr, 2019. 178(1): p. 21–32.

69. Parikh, S., R. Saneto, M.J. Falk, I. Anselm, et al., A modern approach to the treatment of mitochondrial disease. Curr Treat Options Neurol, 2009. 11(6): p. 414–30.

70. Mancuso, M., M.T. Papadopoulou, Y.S. Ng, A. Ardissone, et al., Management of seizures in patients with primary mitochondrial diseases: consensus statement from the InterERNs Mitochondrial Working Group. Eur J Neurol, 2024. 31(7): p. e16275.

71. Na, J.H. and Y.M. Lee, Therapeutic Approach to Epilepsy in Patients with Mitochondrial Diseases. Yonsei Med J, 2025. 66(3): p. 131–140.

72. Ratnaike, T.E., N. Elkhateeb, A. Lochmuller, C. Gilmartin, et al., Evidence for sodium valproate toxicity in mitochondrial diseases: a systematic analysis. BMJ Neurol Open, 2024. 6(1): p. e000650.

73. Hommet, C., K. Mondon, B. de Toffol, and T. Constans, Reversible cognitive and neurological symptoms during valproic acid therapy. J Am Geriatr Soc, 2007. 55(4): p. 628.

74. Straussberg, R., S. Kivity, R. Weitz, L. Harel, et al., Reversible cortical atrophy and cognitive decline induced by valproic acid. Eur J Paediatr Neurol, 1998. 2(4): p. 213–8.

75. De Michele, G., P. Sorrentino, C. Nesti, A. Rubegni, et al., Reversible Valproate-Induced Subacute Encephalopathy Associated With a MT-ATP8 Variant in the Mitochondrial Genome. Front Neurol, 2018. 9: p. 728.

76. Chang, C.C., P.S. Chen, J.R. Lin, Y.A. Chen, et al., Mitochondrial DNA Copy Number Is Associated With Treatment Response and Cognitive Function in Euthymic Bipolar Patients Receiving Valproate. Int J Neuropsychopharmacol, 2022. 25(7): p. 525–533.

77. Yoon, H.Y., M.H. Ahn, J. Yee, N. Lee, et al., Influence of CYP2C9 and CYP2A6 on plasma concentrations of valproic acid: a meta-analysis. Eur J Clin Pharmacol, 2020. 76(8): p. 1053–1058.

78. Yazbeck, H., J. Youssef, W. Nasreddine, A. El Kurdi, et al., The role of candidate pharmacogenetic variants in determining valproic acid efficacy, toxicity and concentrations in patients with epilepsy. Front Pharmacol, 2024. 15: p. 1483723.

79. Zheng, X.X., Y.X. You, L.L. Zhao, Y. Du, et al., Effects of UGT1A, CYP2C9/19 and ABAT polymorphisms on plasma concentration of valproic acid in Chinese epilepsy patients. Pharmacogenomics, 2023. 24(3): p. 153–162.

80. Saleh Faisal, M., A. Jamil, N. Ali, A.M. Alshahrani, et al., Distribution pattern of UGT1A6 and UGT2B7 gene polymorphism and its impact on the pharmacokinetics of valproic acid and carbamazepine: Prospective genetic association study conducted in Pakistani patients with epilepsy. Gene, 2024. 892: p. 147886.

81. Song, C., X. Li, H. Zhang, J. Bao, et al., Impact of MDR1 and UGT Gene Polymorphisms on Sodium Valproate Plasma Concentration in Patients with Epilepsy. Clin Lab, 2022. 68(10).

82. Banawalikar, N., S. Adiga, U. Adiga, V. Shenoy, et al., Association of UGT1A6 gene polymorphism with clinical outcome in pediatric epileptic patients on sodium valproate monotherapy. Braz J Med Biol Res, 2021. 54(9): p. e11097.

83. Yin, Z. and P. Li, Association of UGT1A6 gene polymorphisms with sodium valproate-induced tremor in patients with epilepsy. Seizure, 2024. 120: p. 56–60.

84. Yu, M., Y. Zhao, F. Zhou, W. Li, et al., Effect of UGT1A6 and UGT2B7 polymorphisms on the valproic acid serum concentration and drug-induced liver injury. Pharmacogenomics, 2024. 25(12-13): p. 527–538.

85. Nandith, P.B., U. Adiga, V. Shenoy, and M.N.S. Adiga, UGT1A6 and UGT2B7 Gene Polymorphism and its Effect in Pediatric Epileptic Patients on Sodium Valproate Monotherapy. Indian J Pediatr, 2021. 88(8): p. 764–770.

86. Mei, S., W. Feng, L. Zhu, X. Li, et al., Effect of CYP2C19, UGT1A8, and UGT2B7 on valproic acid clearance in children with epilepsy: a population pharmacokinetic model. Eur J Clin Pharmacol, 2018. 74(8): p. 1029–1036.

87. Parikh, S., A. Goldstein, M.K. Koenig, F. Scaglia, et al., Diagnosis and management of mitochondrial disease: a consensus statement from the Mitochondrial Medicine Society. Genet Med, 2015. 17(9): p. 689–701.

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance with nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.

## Tests in GTR by Condition

Valproic acid response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN078027&term=CN078027[DISCUI]&display_string=Valproic acid response)

## Tests in GTR by Gene

POLG gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=5428[geneid]+AND+CN078027[cui])