# Stroke and Diabetes in Adults

## Summary

Diabetes is a risk factor for both incident and recurrent stroke. Stroke etiology in persons with diabetes is similar to that in the general population and is often associated with large artery atherosclerosis, cardioembolism, and cerebral small vessel disease. A unique feature of stroke in persons with diabetes is that they tend to have more subclinical strokes and different magnetic resonance imaging characteristics of stroke, including more white matter hyperintensities, lacunar infarcts, and other evidence of small vessel disease in the brain. Standard vascular risk factors, including hypertension, smoking, dyslipidemia, and atrial fibrillation, increase the risk of stroke among individuals with both type 1 and 2 diabetes, and treatment of hypertension is a cornerstone of stroke prevention in persons with diabetes. Diabetes-specific stroke risk factors include hyperglycemia, glycemic variability, metabolic syndrome and insulin resistance, albuminuria, and diabetic retinal diseases. Other predictors of stroke risk among persons with diabetes include proteomic biomarkers, obstructive sleep apnea, and autonomic neuropathy.

While epidemiologic studies have found an association between hyperglycemia and stroke risk, randomized clinical trials of intensive glycemic control have not demonstrated a reduction in stroke risk. However, specific glycemic control agents, including the glucagon-like peptide-1 analogues semaglutide and dulaglutide, have been shown to reduce stroke risk in high-risk persons with type 2 diabetes. Further, a thiazolidinedione has been shown to reduce risk of recurrent stroke among persons with type 2 diabetes (PROactive trial) and to prevent recurrent cardiovascular disease events in patients with recent stroke or transient ischemic attack with insulin resistance but not diabetes. Diabetes is associated with higher post-stroke mortality and worse neurologic and functional outcomes, although results have not been consistent across all studies. Despite higher degree of hyperglycemia being associated with worse outcomes in epidemiologic studies, intensive glucose control following an acute ischemic stroke has not been shown to improve outcomes compared with standard glucose control.

## Introduction

In the United States, stroke remains the fifth leading cause of death (1). In 2022, the prevalence of stroke in the general population was roughly 3.3%–3.4%. The prevalence is expected to increase substantially with the aging of the U.S. population. Diabetes is an independent risk factor for incident stroke. A meta-analysis based on 698,782 people from 102 prospective studies showed that diabetes is associated with hazard ratios (HR) of 2.27 (95% confidence interval [CI] 1.95–2.65) for ischemic stroke and 1.56 (95% CI 1.19–2.05) for hemorrhagic stroke (2). Diabetes is also associated with stroke recurrence and risk of several adverse post-stroke outcomes (3). Strategies to reduce the rising stroke burden need to target high-risk subgroups of the population, including those with diabetes. This article describes the epidemiology of stroke, risk factors for stroke, control of stroke risk factors, acute stroke treatment, and prognosis following stroke among persons with diabetes. It provides a comprehensive and contemporary review of the current state of stroke in adults with diabetes in the United States and updates the Diabetes in America, 3rd edition, chapter Stroke and Diabetes (4).

## Sources and Limitations of National Data on Stroke and Diabetes

Population-level data on stroke and diabetes are available from several surveys conducted in the United States that use national probability samples, including the National Health Interview Survey (NHIS), the National Health and Nutrition Examination Survey (NHANES), and the Behavioral Risk Factor Surveillance System (BRFSS). These data sources are briefly described.

The NHIS is a cross-sectional household interview survey that uses a complex sampling design and has been conducted continuously since 1957. In the NHIS 2022–2023 survey cycles, participants were asked questions about diabetes and stroke status, as well as sociodemographic characteristics (age, sex, race/ethnicity, education, poverty income ratio, insurance status, and place of residence). Diagnosed diabetes was determined if participants answered “yes” to the following question: “(If female, other than during pregnancy) Have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Participants were also asked about the type of diabetes, continuous insulin use status, and current insulin use status. Defining type of diabetes based on this information is not entirely accurate due to the lack of a gold standard or antibody testing, but participants who self-report type 1 diabetes, have continuous insulin use within one year of diagnosis, and currently use insulin were determined to have probable type 1 diabetes (N=222). Stroke was determined if participants answered “yes” to the following question: “Have you ever been told by a doctor or health professional that you had a stroke?” Limitations of the NHIS are that the data are self-reported and persons with undiagnosed diabetes cannot be identified. NHIS 2022–2023 data were used to assess current stroke prevalence by sociodemographic characteristics among adults with any diagnosed diabetes, diagnosed type 2 diabetes (defined as self-report of diagnosed diabetes and not defined as probable type 1 diabetes), and no diagnosed diabetes. Data on Asian American subgroups and Hispanic subgroups, other than Mexican American persons, were not publicly available for analysis.

The NHANES is a cross-sectional, national probability sample that has been conducted periodically since 1971 and continuously since 1999. Participants self-reported diagnosed diabetes status, based on the question of “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” An advantage of the NHANES is the inclusion of a health exam in a mobile examination center where laboratory measures are collected. Thus, the NHANES has laboratory information on glycated hemoglobin (A1C) and fasting plasma glucose (FPG) to determine undiagnosed diabetes (no self-report of diagnosed diabetes and A1C ≥6.5% [≥48 mmol/mol] or FPG ≥126 mg/dL [≥7.0 mmol/L; fast 8–24 hours]) and prediabetes (no self-report of diagnosed diabetes and A1C 5.7%–6.4% [39–46 mmol/mol)] or FPG 100–<126 mg/dL [5.6–<7.0 mmol/L; fast 8–24 hours]). The NHANES does not include a question on diabetes type; therefore, no distinction is made between type 1 and type 2 diabetes with this data source. Participants self-reported any history of stroke and demographic characteristics (age, sex, race/ethnicity). In this article, NHANES data collected from individuals for the period 2017–2020 Q1 and August 2021–August 2023 were used to estimate stroke prevalence by age, sex, and race/ethnicity among adults with diagnosed diabetes, undiagnosed diabetes, prediabetes, and normal glycemia. The 18-month NHANES data gap was due to the COVID-19 (coronavirus disease of 2019) pandemic. In addition, data from survey periods between 1988–1994 and 1999–2023 were used to assess trends in stroke and diabetes prevalence.

The BRFSS is a large, state-based telephone survey conducted annually to collect data on respondents’ health-related behaviors, chronic health conditions, and use of preventive services. Diagnosed diabetes was determined if participants answered “yes” to the following question: “(If female, other than during pregnancy) Have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Participants self-reported any history of stroke and demographic characteristics (age, sex, and race/ethnicity). Data from 2022–2023 were utilized to estimate current stroke prevalence by age, sex, race/ethnicity, and state or territory of residence among adults with diagnosed diabetes and without diagnosed diabetes. While data in the BRFSS are self-reported, an advantage of the survey is the ability to assess state-level estimates that are representative of each state’s population.

The Healthcare Cost & Utilization Project (HCUP), National (Nationwide) Inpatient Sample (NIS) is the largest publicly available all-payer inpatient healthcare database designed to produce U.S. national estimates of in-patient utilization, access, cost, quality, and outcomes. The HCUP-NIS includes approximately 35 million hospitalizations nationally. Diabetes status and type are determined using ICD-10 (International Classification of Diseases, Tenth Revision) codes. Stroke and transient ischemic attack (TIA) are identified from the Chronic Conditions Warehouse (CCW) with at least one inpatient discharge listing stroke. Data from the HCUP-NIS 2021 were used to estimate incidence of inpatient hospital discharges listing stroke among adults with any type of diabetes (ICD-10 codes E10–E14), type 2 diabetes only (ICD-10 code E11), type 1 diabetes only (ICD-10 code E10), and without diabetes.

### Statistical Methods

All results from the national surveys were statistically weighted to produce estimates that are nationally representative of the noninstitutionalized U.S. population. The weighted standard errors are provided for estimates in the tables and weighted 95% confidence intervals are provided in figures. Percent estimates were considered significantly different if 95% confidence intervals prepared with weighted standard errors did not overlap. In cases where the sample size is small and the estimates may not be reliable and representative of the population, the relative standard error (RSE = [SE/estimate]*100) is provided in tables and figures. If RSEs are >50%, the results are not shown. Estimates of crude prevalence are provided in the text with age-standardized estimates (standardized to the NHIS 2022–2023 population with diabetes) included in the appendix tables, except for estimates by race/ethnicity where both crude and age-standardized estimates are provided. Unless stated otherwise, adults refer to persons age ≥20 years (with a coding cap at age 85 years, except for results based on BRFSS, where age is capped at 80 years), and youth refers to persons age <20 years at the time of the survey. Race and ethnicity are combined into one variable, race/ethnicity, by categorizing everyone with Hispanic ethnicity as Hispanic, regardless of race, and then categorizing everyone with non-Hispanic ethnicity based on their race.

## Literature Review Strategy

The summary of the published literature focuses on published meta-analyses, as well as U.S. clinical trials and cohort studies, whenever possible. When data from these types of studies were scarce, evidence from lesser quality observational studies is summarized. If limited U.S.-based studies on a specific topic were identified, non-U.S.-based studies are also included. Where studies reporting results for stroke as a primary or secondary outcome were rare, research that included stroke as a component of cardiovascular disease (CVD) are included and summarized.

## Pathophysiology of Stroke in Persons With Diabetes

### Classification of Stroke Type and Subtype

Stroke is clinically defined as an acute onset of a focal neurological deficit persisting for more than 24 hours (5). About 85% of all strokes in the United States are ischemic, and the other 15% are hemorrhagic. Ischemic stroke is caused by an abrupt blockage of the artery, either by an embolus from the heart or from a more proximal artery, or from an in situ thrombus growing to occlude a cerebral artery affected by an atherosclerotic plaque, leading to insufficient blood supply to the brain (6). Hemorrhagic stroke is caused by an abrupt rupture of the artery, leading to blood accumulation in the substrate of the brain, in the cerebrospinal fluid around the brain, or in the cerebrospinal fluid spaces within the brain (6).

Ischemic strokes are classified further based on presumed etiology. A commonly utilized classification of subtypes of ischemic stroke is the TOAST classification, named for the Trial of Org 10172 in Acute Stroke Treatment, the clinical trial in which this system was initially developed (7). An alternative, more automated system used in genetic analyses is the Causative Classification of Stroke System (8). In both classification systems, ischemic strokes are subdivided into five categories as being due to: (1.) large artery atherosclerosis, (2.) cardioembolism, (3.) cerebral small vessel disease (CSVD) or lacunar strokes, (4.) stroke of other determined etiology, and (5.) stroke of undetermined etiology. Hemorrhagic strokes are categorized as subarachnoid hemorrhage (SAH) or intracerebral hemorrhage (ICH) (9). SAHs are due to rupture of an aneurysm, typically in the large intracranial arteries, into the subarachnoid space. ICHs are further categorized as lobar (in the cerebral hemispheres) or deep (in the basal ganglia, thalami, brainstem, or cerebellum) (9).

Persons with diabetes have about twice the risk for stroke, particularly ischemic stroke, compared to persons without diabetes (10). Although the etiology of stroke in persons with diabetes is comparable to the etiology in the general population, multiple underlying pathophysiological processes in diabetes lead to a different distribution of stroke type and ischemic stroke subtype (11,12,13). The frequency of hemorrhagic strokes in person with diabetes is similar or slightly less than that in the general population (14,15). Diabetes causes atherosclerotic changes in the heart and cerebral arteries and is associated with an increased risk of different subtypes of ischemic stroke, including large artery atherosclerosis, cardioembolism, and CSVD strokes (16).

Among persons with diabetes, hyperglycemia, insulin resistance, and dyslipidemia lead to accelerated macrovascular injury (17). This includes physiological changes in the macrovascular bed, such as reduced availability of nitric oxide, increased oxidative stress, chronic low-grade inflammation, increased sympathetic tone, and changes in the type or structure of elastin and/or collagen in the arterial wall (11). All of these processes lead to accelerated development of atherosclerotic lesions and plaque rupture of large vessels (18), contributing to an increased risk of large artery atherosclerosis stroke among individuals with diabetes.

Individuals with type 2 diabetes have a higher risk of developing atrial fibrillation (AF) compared to people without diabetes (19). Higher levels of reactive oxygen species and/or advanced glycation end products (AGEs) in diabetes may cause changes in atrial electrical, structural, and autonomic functions, leading to remodeling (atrial cardiomyopathy) and an increased risk of AF (20). AF and the inflammatory processes among individuals with diabetes induce thrombosis, leading to cardioembolic strokes due to the formation of blood clots in the heart that travel to the brain (21).

Cerebral microvascular dysfunction is also evident in individuals with diabetes (13,22). Hyperglycemia, insulin resistance, and dyslipidemia among individuals with diabetes lead to microvascular endothelial dysfunction through increased oxidative stress and inflammation (22). Microvascular endothelial dysfunction exposes small cerebral vessels within deep brain structures to abnormal pulsatile flow, contributing to the pathogenesis of CSVD (22).

Prolonged hyperglycemia among individuals with diabetes may result in renal dysfunction, which may contribute to a greater stroke risk (23,24). If renal dysfunction is not effectively treated, moderately elevated albuminuria is followed by slowly progressive severely elevated albuminuria and/or decreases in estimated glomerular filtration rate. This may be accompanied by diabetic autonomic neuropathy. Each of these conditions may contribute to the pathophysiology of stroke through accelerated cerebral vascular damage and alterations in the regulation of cerebral blood flow (23,24,25,26,27).

### Clinical Presentation of Stroke in Persons With Diabetes

Most ischemic strokes present with symptoms of (a) anterior cerebral circulation (carotid artery territory) involvement, such as an acute loss of motor power and sensory deficits on one side of the body (face, arm, and leg), aphasia, visual deficits, or sensory neglect or (b) posterior cerebral circulation (vertebrobasilar) involvement with presenting symptoms of dizziness or vertigo, double vision, balance, gait dysfunction or weakness, and sensory deficits (6). Hemorrhagic strokes typically present with more pronounced headaches, neck pain, light intolerance, nausea and vomiting, and impaired level of consciousness than ischemic strokes (6).

Although the number and severity of standard vascular risk factors are higher in stroke patients with diabetes than those without it (28,29,30), the size and severity of stroke are comparable between these two groups (28,31). However, there are some specific clinical patterns of ischemic stroke in individuals with diabetes, in whom a higher prevalence of posterior circulation than anterior infarctions have been reported (29,32,33).

## Epidemiology of Stroke in the General Population and Persons With Diabetes

### Prevalence and Incidence of Stroke in the General Population

The prevalence of self-reported stroke by age and sex in the general population, based on data from the NHANES 2017–2023, was low at younger ages but rose to ~7%–8% in persons age 60–79 years and to ~14% in those age ≥80 years (1). The prevalence was similar by sex. In the Framingham Heart Study (FHS), however, women had a higher lifetime risk of stroke (20%–21%) compared to men (14%–17%) (34).

The incidences of first stroke in the general population by race and year (1993–2015) and by sex and year are shown in Figures 1 and 2, respectively, based on data from the Greater Cincinnati/Northern Kentucky Stroke Study (GCNKSS) population (35,36). The stroke incidence (of any type) was 1.4 to 4.2 times higher in Black persons than White persons, and this difference by race was stable over time (35). The incidence was higher in men than in women and declined significantly for both sexes over time (36). The vast majority of stroke incidence was due to ischemic events.

Several other population-based studies have also provided insight into racial and ethnic differences in stroke risk in the general population (1,37,38,39). The overall findings suggest an excess stroke risk among Black, Hispanic, and American Indian populations compared to the White population. In the Atherosclerosis Risk in Communities (ARIC) study, a Black-to-White HR for stroke of 1.96 (95% CI 1.41–2.71) was observed after adjusting for age, sex, diabetes, smoking, and AF (37). The Northern Manhattan Study (NOMAS) showed an age- and sex-adjusted Hispanic-to-White incidence ratio of 1.48 (95% CI 1.13–1.93) (38). The crude incidence rate of first ischemic stroke was 13 per 1,000 person-years in Black persons, 10 per 1,000 person-years in Hispanic persons, and 9 per 1,000 person-years in White persons, according to data from the NOMAS (38). In the Strong Heart Study, the unadjusted HRs for incident stroke comparing American Indian to White persons (from ARIC) varied from 1.29 to 3.52 by the birth year of study participants (39).

### Prevalence and Incidence of Stroke in Persons With Type 2 Diabetes

Among adults with and without diabetes in the NHIS 2022–2023, the crude prevalences of stroke were 8.7% among adults with diagnosed diabetes (any type) and 8.8% among adults with type 2 diabetes, which were substantially higher compared to the prevalence in those without diabetes (2.4%) (Table 1). In the NHANES 2017–2023, the prevalence of stroke was the highest for adults with diagnosed diabetes (10.6%), of whom the vast majority have type 2 diabetes, lower among adults with undiagnosed diabetes (6.4%) or prediabetes (3.3%), and lowest among adults with normal glucose levels (1.8%) (Table 2). Age-standardized prevalences of stroke are shown in Appendix Table A1 and Appendix Table A2 from the NHIS 2022–2023 and NHANES 2017–2023, respectively.

The crude incidence of hospitalization due to stroke among adults with and without diabetes from the HCUP-NIS 2021 is shown in Table 3. The crude incidence in adults with type 2 diabetes was 4.9%, while the incidence in adults without diabetes was 3.2%. Age-standardized incidence rates are shown in Appendix Table A3.

Nurses’ Health Study (NHS) data from 1976–2002 were used to evaluate the risk of stroke in women with type 2 diabetes (15). The study utilized biennially mailed questionnaires to evaluate participants’ medical status. Participants were categorized as having type 1 diabetes if they were diagnosed with diabetes before age 30 years and reported use of insulin or a history of ketosis. All others were categorized as having type 2 diabetes. Among 10,766 women with type 2 diabetes in the NHS, mean age at baseline was 55.3 years and mean diabetes duration was 11.4 years. Table 4 shows incidence rates for stroke subtypes by diabetes status during 24 years of follow-up. The overall stroke incidence rate was about two times higher among women with type 2 diabetes (2.4 per 1,000 person-years) than those without diabetes (0.92 per 1,000 person-years). The limitations of this analysis were the use of mailed questionnaires to establish medical history and the fact that fewer than three-fourths of all historical stroke events could be confirmed by medical record review.

In the REasons for Geographic and Racial Differences in Stroke (REGARDS) study (2003–2007), among 23,002 non-Hispanic Black and non-Hispanic White persons age ≥45 years without prevalent stroke at baseline, 19.1% had diabetes at baseline defined as a FPG ≥126 mg/dL, random glucose ≥200 mg/dL (≥11.1 mmol/L), or use of a glucose-lowering medication (40). During a median follow-up of 9.8 years, 1,018 stroke events occurred (ischemic stroke, n=914; hemorrhagic stroke, n=104). The crude stroke incidence rate for those with diabetes was 7.55 per 1,000 person-years (95% CI 6.70–8.51) compared to 4.48 per 1,000 person-years (95% CI 4.17–4.82) for those without diabetes. This study was not able to differentiate between type 1 and type 2 diabetes, but the majority of REGARDS participants likely had type 2 diabetes given the older age of the participants (mean age 64 years at baseline). The mean duration of diabetes was also not known.

### Prevalence and Incidence of Stroke in Persons With Type 1 Diabetes

Data from the HCUP-NIS 2021 showed that the hospitalization rate due to stroke in adults with type 1 diabetes was 2.2% compared to 3.2% in adults without diabetes (Table 3). Age-standardized incidence rates are shown in Appendix Table A3.

Data on the incidence of stroke in persons with type 1 diabetes are limited to older cohorts that may not be reflective of contemporary management. Nonetheless, we present this data given the limited availability of more recent estimates.

In the Wisconsin Epidemiologic Study of Diabetic Retinopathy, among 996 children and adults with type 1 diabetes recruited between 1980 and 1982, the 20-year age-adjusted cumulative incidence of stroke was 5.9% (41).

In the Pittsburgh Epidemiology of Diabetes Complications study (EDC), among 658 participants with childhood-onset type 1 diabetes followed for a mean duration of 15.4 years, 31 participants (mean age 40.2 years) experienced strokes (42). Participants with stroke were older and had longer durations of type 1 diabetes (mean duration 25 years) than persons without stroke (mean age 27.3 years, mean duration of diabetes 19 years). There was no difference in stroke risk based on sex or race. Although the number of stroke events was small, the overall survival rates regardless of stroke type were 80.6%, 45.2%, and 9.6% at 1, 5, and 10 years, respectively.

Over a follow-up period of 6 years, approximately 3% of a cohort of Black persons with type 1 diabetes, assembled from hospital discharges with a diagnosis of diabetes in New Jersey, developed a stroke (43). Significant limitations of this study were the hospital-based nature of the cohort and the lack of nondiabetic and White comparison groups (43).

The NHS evaluated the risk of stroke in 303 women with type 1 diabetes, whose mean age at baseline was 52.4 years and duration of diabetes was 31.4 years (15). During 24 years of follow-up (baseline from 1976 to 2002), the overall stroke incidence rate was about five times higher among women with type 1 diabetes (4.75 per 1,000 person-years) than those without diabetes (0.92 per 1,000 person-years). The stroke incidence rates were significantly higher among women with type 1 diabetes than among women with type 2 diabetes (Table 4).

### Age Differences in Prevalence and Incidence of Stroke in Persons With Diabetes

Figure 3 and Table 1 show crude stroke prevalences among adults with diagnosed diabetes and without diabetes stratified by age groups in the NHIS 2022–2023. Stroke prevalence among adults with diagnosed diabetes increased with advancing age, with 2.7% of adults age 20–44 years reporting a history of stroke compared to 16.0% of adults age ≥85 years. A similar pattern was observed for adults with type 2 diabetes. Stroke prevalence increased with increasing age for adults without diabetes; however, the absolute prevalence was lower, ranging from 0.5% for adults age 20–44 years to 11.3% for adults ≥85 years. In the NHANES 2017–2023 (Table 2), stroke prevalence increased with age for adults with diagnosed diabetes, ranging from 3.7% for adults age 20–44 years to 16.9% for adults age 65–74 years; among adults age ≥75 years, 24.0% with undiagnosed diabetes and 13.1% with prediabetes reported a history of stroke. In each age group, the prevalence of stroke was significantly higher among those with diabetes than those without diabetes (Tables 1 and 2).

The crude incidence of hospitalization due to stroke among adults with diabetes from the HCUP-NIS 2021 also increased with advancing age (Table 3). Similar patterns were observed among adults with type 1 diabetes and those with type 2 diabetes.

In the Honolulu Heart Program, 7,589 Japanese American men (mean age 55 years) free of history of stroke at baseline were followed for 12 years (44). Incidence rates increased significantly with age for hemorrhagic stroke among 690 men with diabetes and for both thromboembolic and hemorrhagic stroke among 6,908 men without diabetes.

In the Wisconsin Epidemiologic Study of Diabetic Retinopathy, statistically significant differences were observed in the 20-year age-adjusted cumulative incidences of stroke by baseline age (41). The incidence was 1.3%, 0.0%, 3.3%, 8.1%, and 20% for individuals with a baseline age of 10.0–14.9, 15.0–19.9, 20.0–29.9, 30.0–44.9, and ≥45.0 years, respectively (41). Note, these data are from an older cohort, but more recent estimates of stroke incidence in younger populations are not available.

In the GCNKSS study (1993–2005), among residents age ≥20 years, there were 1,709 first-ever ischemic strokes in 1993–1994, 1,778 in 1999, and 1,680 in 2005 (45). In 1993–1994, 493 (28%) individuals had a documented history of diabetes diagnosed before stroke compared with 522 (29%) in 1999 and 544 (33%) in 2005. In the overall study period (1993–2005), stroke incidence rates increased with increasing age among individuals with diabetes, similar to the pattern among individuals without diabetes (Table 5). In all age groups, the incidence rate ratio (IRR) for stroke comparing individuals with diabetes to those without diabetes was greater than one and was the highest among those age 20–44 years. The IRR for stroke decreased with increasing age. In the GCNKSS, individuals with diabetes may be undercounted, as only those with a diagnosis of diabetes mellitus documented in the medical record before stroke were identified; undiagnosed diabetes, i.e., elevated FPG or A1C, was not classified as diabetes for this study. Therefore, the incidence rates in this study could be underestimated.

In REGARDS, the IRR for stroke comparing those with diabetes to those without diabetes was also greater than one and higher among individuals age <65 years at baseline than those age ≥65 years at baseline, except for Black men (Table 6) (40).

### Sex Differences in Prevalence and Incidence of Stroke in Persons With Diabetes

Regardless of diabetes status, the prevalence of stroke is similar for men and women (Tables 1 and 2). In the NHIS 2022–2023, the crude prevalence of stroke among adults with diagnosed diabetes was 8.3% for men and 9.1% for women compared to 2.3% for men and 2.4% for women without diabetes (Table 1). Prevalence of stroke was similar by sex for adults with diagnosed diabetes and those with type 2 diabetes, where adults with probable type 1 diabetes were removed. The age-sex stratified stroke prevalence among adults with diagnosed diabetes and without diabetes based on data from the NHIS 2022–2023 is shown in Figure 4. Regardless of diabetes status, the stroke prevalence was similar for men and women in each age group. In the NHANES 2017–2023, the crude prevalence of stroke among men with undiagnosed diabetes was lower compared to women with undiagnosed diabetes (2.5% vs. 10.6%, respectively) (Table 2). Age-standardized prevalences are shown in Appendix Table A1 and Appendix Table A2 from the NHIS 2022–2023 and NHANES 2017–2023, respectively.

In the HCUP-NIS 2021, the crude incidence of hospitalized stroke among adults with type 2 diabetes was 4.9% for men and 4.6% for women (Table 3); the corresponding rates for type 1 diabetes were 2.4% and 2.0%, respectively. In adults without diabetes, the incidence rate of hospitalized stroke was 3.9% for men and 2.7% for women. Age-standardized incidence rates are shown in Appendix Table A3.

In the Wisconsin Epidemiologic Study of Diabetic Retinopathy, no significant sex differences in the 20-year age-adjusted cumulative incidences of stroke were found (41). The incidence was 4.0% for women and 6.5% for men.

In REGARDS, among those with diabetes, there were no sex differences in the incidence rate of stroke for those age <65 years; for those age ≥65 years, White women (11.97 per 1,000 person-years, 95% CI 8.72–16.43) tended to have a higher incidence rate of stroke than White men (8.17 per 1,000 person-years, 95% CI 6.03–11.06), while Black women (8.44 per 1,000 person-years, 95% CI 6.35–11.21) tended to have a lower incidence rate of stroke than Black men (11.18 per 1,000 person-years, 95% CI 8.25–15.16 (Table 6) (40). The IRR for stroke comparing those with diabetes to those without diabetes was not significantly different between women and men, except among White persons age ≥65 years; in this race and age group, the IRR was larger in women (IRR 1.92, 95% CI 1.35–2.74) than in men (IRR 1.01, 95% CI 0.73–1.41).

### Racial and Ethnic Differences in Prevalence and Incidence of Stroke in Persons With Diabetes

In the NHIS 2022–2023, the crude prevalence of stroke among adults with diagnosed diabetes was the highest for non-Hispanic American Indian or Alaska Native persons (10.6%), followed by non-Hispanic Black (9.6%), non-Hispanic White (9.3%), Hispanic (7.6%), and non-Hispanic Asian (4.8%) persons (Table 1). The associations by race/ethnicity were similar for those with type 2 diabetes and without diabetes. The age-standardized prevalence of stroke among adults with diagnosed diabetes tended to be the highest for non-Hispanic American Indian or Alaska Native persons (12.2%), followed by non-Hispanic Black (9.8%), non-Hispanic White (8.9%), Hispanic (8.2%; 6.5% for Mexican American, 10.4% for other Hispanic), and non-Hispanic Asian (4.6%) persons; the corresponding prevalences for type 2 diabetes were similar (Appendix Table A1).

The crude stroke prevalence in the NHIS 2022–2023 stratified by age and race/ethnicity among adults with diagnosed diabetes and without diabetes is shown in Figure 5. Among adults with diabetes age 20–64 years, the stroke prevalence was the highest for non-Hispanic Black persons followed by Hispanic and non-Hispanic White persons. Among individuals with diabetes age ≥65 years, the stroke prevalence was similar for non-Hispanic White, non-Hispanic Black, and Hispanic persons. The prevalence of stroke was the lowest for non-Hispanic Asian persons and the highest for non-Hispanic American Indian or Alaska Native persons; however, the sample sizes were small for these subgroups, which resulted in unstable estimates. Among adults without diabetes, the pattern of stroke prevalence by race/ethnicity was similar across the younger and older age groups; the prevalence was the highest for non-Hispanic American Indian or Alaska Native persons, second highest for non-Hispanic Black persons, similar between non-Hispanic White and Hispanic persons, and lowest for non-Hispanic Asian persons.

In the NHANES 2017–2023, the prevalence of stroke was 9.2% for non-Hispanic White adults and 5.3% among non-Hispanic Black adults with undiagnosed diabetes; other race/ethnicity subgroups were too small to produce reliable estimates (Table 2). Among adults with prediabetes, stroke prevalence was similar for non-Hispanic White and non-Hispanic Black adults. Age-standardized prevalences of stroke by race/ethnicity are shown in Appendix Table A2.

In the BRFSS 2022–2023, both crude (Table 7) and age-standardized (Appendix Table A4) stroke prevalence among adults with diagnosed diabetes tended to be the highest for non-Hispanic multiracial (crude 12.2%, age-standardized 13.3%) and non-Hispanic other race (crude 12.6%, age-standardized 12.5%) persons, followed by non-Hispanic Black (crude 11.6%, age-standardized 11.8%), non-Hispanic American Indian or Alaska Native (crude 9.4%, age-standardized 10.2%), non-Hispanic White (crude 9.6%, age-standardized 9.3%), non-Hispanic Native Hawaiian/Other Pacific Islander (crude 8.0%, age-standardized 9.4%), Hispanic (crude 7.8%, age-standardized 7.9%), and non-Hispanic Asian (crude 6.3%, age-standardized 6.5%) persons.

Based on data from the HCUP-NIS 2021, both crude (Table 3) and age-standardized (Appendix Table A3) incidence of hospitalized stroke among adults with type 2 diabetes tended to be the highest for Asian/Pacific Islander persons (crude 6.5%, age-standardized 6.2%), followed by Black (crude 5.7%, age-standardized 5.6%), Hispanic (crude 4.7%, age-standardized 4.7%), White (crude 4.6%, age-standardized 4.3%), and Native American (crude 3.7%, age-standardized 3.9%) persons. The corresponding crude and age-standardized rates for type 1 diabetes were 3.3% and 5.1%, 1.8% and 4.1%, 2.0% and 4.8%, 2.3% and 3.4%, and 1.4% and inestimable, respectively.

In the Honolulu Heart Program, the incident stroke rate was 62.3 per 1,000 person-years among men with diabetes (mean age 55.6 years) and 32.7 per 1,000 person-years among men without diabetes (mean age 54.2 years) (44). The estimated HR of stroke for those with diabetes compared with those without diabetes was 1.7 (95% CI 1.2–2.3). In a subsequent study that compared 20-year incidence of hospitalized stroke among 7,589 Japanese American men in the Honolulu Heart Program and 1,216 White men in the FHS with or without diabetes (46), researchers found that diabetes was associated with about twofold excess risk of thromboembolic stroke in Japanese American men but more than threefold in White men. Moreover, diabetes was not a risk factor for hemorrhagic stroke in Japanese American men but was associated with four- to fivefold excess risk of hemorrhagic stroke in White men.

In the Strong Heart Study, a population-based study of 4,507 American Indian participants (mean age 59.5 years) who were free of prevalent stroke at baseline, 2,196 had diabetes, 891 had impaired glucose metabolism, and 1,332 had normal glucose tolerance at baseline (47). Of these groups, 211, 43, and 50 individuals had incident strokes, respectively, over a 12–15-year follow-up period, resulting in age- and sex-adjusted incidence rates of 8.87, 3.93, and 3.12 per 1,000 person-years, respectively. The HR for stroke comparing those with diabetes to those with normal glucose tolerance was 2.05 (95% CI 1.41–3.00), while there was no difference between those with impaired glucose metabolism and those with normal glucose tolerance. In this study, diabetes was defined by the 1998 Provisional World Health Organization Report (FPG ≥126 mg/dL or post-75 g oral glucose challenge blood glucose of ≥200 mg/dL or use of an oral hypoglycemic agent or insulin). Impaired glucose intolerance was defined as FPG <126 mg/dL with post-challenge glucose between 140 and 199.9 mg/dL (7.8–<11.1 mmol/L). Impaired FPG was defined as FPG between 110 and 125.9 mg/dL (6.1–<7.0 mmol/L), with post-challenge glucose <140 mg/dL. Impaired glucose tolerance and impaired FPG were combined as one category designated as “impaired glucose metabolism.” Normal glucose tolerance was defined as FPG <110 mg/dL, with post-challenge glucose <140 mg/dL.

In ARIC, no data on the incidence rate for stroke among individuals with diabetes have been reported (48); however, the adjusted HR for incident stroke comparing those with diabetes to those without diabetes was statistically significantly larger (p=0.02) among Black persons (HR 2.54, 95% CI 2.03–3.18) than among White persons (HR 1.74, 95% CI 1.37–2.21).

Data from the GCNKSS (1993–2005) showed that among individuals with diabetes, the overall incidence rate for stroke in Black persons (6.17 per 1,000 person-years, 95% CI 5.44–6.91) tended to be higher than in White persons (5.60 per 1,000 person-years, 95% CI 5.22–5.98) (Table 5) (45). Among individuals without diabetes, the overall incidence rate for stroke in Black persons (2.33 per 1,000 person-years, 95% CI 2.15–2.52) was significantly higher than in White persons (1.62 per 1,000 person-years, 95% CI 1.57–1.67); however, the IRR for incident stroke comparing those with diabetes to those without diabetes was significantly higher for White persons (IRR 3.5, 95% CI 3.2–3.7) than for Black persons (IRR 2.6, 95% CI 2.3–3.0).

In the GCNKSS, when stratified by age group, the incidence rates for stroke among individuals with diabetes were higher in Black persons age 45–74 years and in White persons age ≥75 years (Table 5) (45). The incidence rates for stroke among individuals without diabetes were statistically significantly higher in Black persons than White persons in all age groups. However, the IRR for stroke comparing individuals with diabetes to those without diabetes was significantly greater for White persons than for Black persons, except for those age 65–74 years, in which the IRR was not different between race groups.

In REGARDS, among those with diabetes, there were no racial differences in the incidence rate of stroke for those age <65 years (Table 6) (40). For those age ≥65 years, White women (11.97 per 1,000 person-years, 95% CI 8.72–16.43) tended to have a higher incidence rate of stroke than Black women (8.44 per 1,000 person-years, 95% CI 6.35–11.21), while White men (8.17 per 1,000 person-years, 95% CI 6.03–11.06) tended to have a lower incidence rate of stroke than Black men (11.18 per 1,000 person-years, 95% CI 8.25–15.16) (Table 6); however, these racial differences were not statistically significant. Among those without diabetes, Black persons age <65 years had a significantly higher incidence rate of stroke; for those age ≥65 years, there was no significant racial difference in the stroke incidence rate. The IRR for stroke comparing those with diabetes to those without diabetes was not significantly different between Black and White persons.

### Social Determinants of Health and Prevalence and Incidence of Stroke in Persons With Diabetes

Table 8 shows the crude prevalence of stroke among adults with and without diabetes by social determinants of health in the NHIS 2022–2023. Among individuals with diabetes, the prevalence of stroke was higher in adults with less education, lower poverty income ratio, with Medicaid, and living in nonmetropolitan areas. Similar patterns were observed among individuals without diabetes. In each level of social determinants of health, the prevalence of stroke was higher among individuals with diabetes than individuals without diabetes. Age-standardized prevalences are shown in Appendix Table A5.

Figure 6 shows the age-standardized prevalence of stroke among adults with and without diabetes by U.S. state or territory of residence, based on data from the BRFSS 2022–2023. Among individuals with diagnosed diabetes (Figure 6A, Appendix Table A6), the prevalence of stroke was the highest in Pennsylvania (14.4%), followed closely by Stroke Belt States (e.g., Arkansas, Louisiana, North Carolina); prevalence of stroke was the lowest in Puerto Rico (4.8%), followed closely by Mountain States. Among individuals without diabetes (Figure 6B, Appendix Table A6), the prevalence of stroke was the highest in the Virgin Islands (7.3%), followed closely by Stroke Belt States (e.g., Alabama, Louisiana); prevalence of stroke was the lowest in Connecticut and Rhode Island (3.3%), followed closely by Mountain States.

### Trends in Prevalence of Stroke

Figures 7 and 8 show temporal trends in the age-standardized prevalence by stroke and diabetes status among women and men, respectively, from the NHANES 1988–2023. Although the prevalences of diabetes and diabetes but no stroke increased over time, the prevalence of diabetes and stroke was relatively stable during the study period.

### Prevalence and Incidence of Stroke in Young Persons With Diabetes

Both prevalence and incidence of stroke are low in young persons with diabetes. Tables 1, 2, and 7 show that the prevalence of stroke among individuals age 20–44 years with diagnosed diabetes was 2.7%–4.7%, depending on the data source.

In 2021, the incidence of hospitalized stroke was 2.1% among individuals age 20–44 years with type 2 diabetes and 1.0% among the same age group with type 1 diabetes (Table 3).

In the Wisconsin Epidemiologic Study of Diabetic Retinopathy, the 20-year age-adjusted cumulative incidences of stroke for individuals with type 1 diabetes were 1.3%, 0.0%, 3.3%, and 8.1% in those with a baseline age of 10.0–14.9, 15.0–19.9, 20.0–29.9, and 30.0–44.9 years, respectively (41).

In the GCNKSS, for individuals with diabetes, incidence rates for ischemic stroke in those age 20–44 years were 1.77 per 1,000 person-years (95% CI 0.84–2.71) for Black persons and 1.28 per 1,000 person-years (95% CI 0.79–1.77) for White persons (Table 5) (45).

### Prevalence and Incidence of Stroke in Persons With Diabetes by Stroke Subtypes

Most studies have shown that diabetes is a risk factor for ischemic stroke, while the incidence of hemorrhagic stroke in individuals with diabetes may be the same as in persons without diabetes (49). In the Honolulu Heart Program, for men with diabetes, incidence rates for thromboembolic strokes (44.9 per 1,000 person-years) were higher than incidence rates for hemorrhagic strokes (10.1 per 1,000 person-years) (44). The estimated HR of thromboembolic stroke for those with diabetes compared with those without diabetes was 1.9 (95% CI 1.3–2.8), while the corresponding HR for hemorrhagic stroke was 0.9 (95% CI 0.4–2.1) (44). In the NHS, for women with either type of diabetes, the incidence rates were the highest for ischemic strokes and the lowest for hemorrhagic strokes (15). For all subtypes of stroke, the incidence rates were higher among individuals with diabetes than those without diabetes, except for the incidence rates for hemorrhagic stroke in individuals with type 2 diabetes (15).

Another common stroke subtype in persons with diabetes is CSVD or lacunar stroke (50,51). The prevalence of diabetes in persons with lacunar stroke is 28%–43% (51). In the NOMAS, a comparison was made between lacunar infarcts and deep ICH, both stroke types occurring as a result of small vessel disease within the deep brain structures, in persons with diabetes; the presence of diabetes conferred threefold higher odds for having a lacunar stroke over a deep ICH (52). In the Cardiovascular Health Study, among 3,660 participants (age >65 years) who underwent brain magnetic resonance imaging (MRI), diabetes was an independent predictor of lacunar infarcts (53). In the NHS, the incidence rate of lacunar infarction among women with type 2 diabetes was 0.5 per 1,000 person-years, about three times higher than the rate among women without diabetes (15).

## Predictors of Stroke Risk in Persons With Diabetes

Vascular risk factors, including hypertension, smoking, dyslipidemia, and AF, have been demonstrated to increase the risk of stroke among individuals with both type 1 and 2 diabetes (54,55,56,57,58), although it remains unclear whether the impact of these factors among persons with diabetes is different or similar to their influence among individuals without diabetes (59,60,61,62,63,64,65,66,67,68,69,70,71,72,73). The single most effective strategy to prevent stroke among persons with diabetes is to ensure optimal blood pressure control. Beyond standard stroke risk factors, research has investigated the impact of diabetes-specific risk factors on stroke risk among persons with diabetes, including hyperglycemia and glycemic variability, metabolic syndrome and insulin resistance, albuminuria, and diabetic retinal diseases, which are summarized in this section. In addition, other predictors of stroke risk, including biomarkers for emerging proteomic risk factors, obstructive sleep apnea (OSA), and autonomic neuropathy, are briefly summarized.

### Diabetes-Specific Predictors of Stroke Risk

#### Hyperglycemia and Glycemic Variability

Hyperglycemia is an independent risk factor for stroke among persons with diabetes. Early research from the NOMAS suggested that elevated FPG was significantly associated with increased risk of incident stroke among 576 individuals with type 2 diabetes after adjusting for standard stroke risk factors (74). A meta-analysis including 18 cohort studies published before 2021 found that the pooled adjusted relative risks for high versus low categories of FPG were 2.18 (95% CI 1.99–2.39) for ischemic stroke and 1.27 (95% CI 1.14–1.42) for hemorrhagic stroke in individuals with or without diabetes, while the relative risks were 1.24 (95% CI 1.12–1.36) and 1.07 (95% CI 0.97–1.18), respectively, in individual without diabetes; these data suggest that higher FPG was associated with higher risk of stroke among persons with diabetes, although a specific comparison was not presented (75). FPG does not reflect postprandial glucose levels, which are associated with glycemic control among patients with diabetes.

A1C reflects both FPG and postprandial glucose levels (76) and is a good indicator of glycemic levels over two to three months. In a meta-analysis including 29 cohort and nested case-control studies published before 2017, every 1% higher A1C increment among persons with diabetes was associated with pooled adjusted HRs of 1.17 (95% CI 1.09–1.25) for first-ever stroke and 1.24 (95% CI 1.11–1.39) for first-ever ischemic stroke (77). Later research found similar associations for incident lacunar infarction, atherothrombotic stroke, and hemorrhagic stroke among individuals with type 2 diabetes (78,79,80). The meta-analysis did not provide results stratified by diabetes type because only two studies, from Sweden and Finland, focused on persons with type 1 diabetes were included. These two studies found that higher A1C values were significantly associated with increased risk of incident stroke in multivariable adjusted models (56,81), consistent with findings from the landmark Diabetes Control and Complications Trial (DCCT) and its observational follow-up, the Epidemiology of Diabetes Interventions and Complications (EDIC) study, as well as the Pittsburgh EDC (82,83,84,85).

Research published after the aforementioned meta-analysis investigated the dose-response relationship between A1C and risk of stroke among persons with type 2 diabetes, with inconsistent findings. Some studies reported a monotonic increase in stroke risk with increasing A1C levels (57,79), while other studies reported a J-shaped or U-shaped association with nadir at A1C 6.0%–7.0% (42–53 mmol/mol) (86,87).

In addition to one-time measures of glycemic levels being predictive of stroke risk among persons with diabetes, long-term glycemic variability has been found to be an independent stroke risk factor. High variability can occur in the setting of insulin deficiency or with fluctuations from high to normal to low glucose. Glycemic variability is typically defined by the measurement of fluctuations in glucose or other related parameters of glucose homeostasis over a given interval of time and assessed as the standard deviation (SD) or the coefficient of variation (CV) of visit-to-visit FPG or A1C. Of the limited number of studies to date that have examined the association between FPG variability and risk of stroke among individuals with type 2 diabetes (88,89,90), all reported a statistically significant association. A meta-analysis that pooled the results of these studies reported that both higher FPG-CV and higher FPG-SD were associated with higher risk of stroke (91), independent of FPG and A1C level, with the pooled risk ratios being 1.33 (95% CI 1.05–1.70) and 1.16 (95% CI 1.02–1.31), respectively. This meta-analysis additionally showed that higher A1C-CV and A1C-SD were both independently associated with higher risk of stroke, with the pooled risk ratios being 1.88 (95% CI 1.61–2.19) and 1.73 (95% CI 1.49–2.00), respectively, among persons with type 2 diabetes based on five cohort studies and post-hoc analysis of clinical trials published before 2021 (90,92,93,94,95). Further research found that this association may be modified by mean A1C level such that the association between A1C-SD and risk of incident stroke was only evident among persons with mean A1C at target (≤7.0%) (96).

Data on the association between A1C variability and risk of incident stroke or CVD among persons with type 1 diabetes are scarce. Findings from the U.S. Coronary Artery Calcification in Type 1 Diabetes follow-up study and the Finnish Diabetic Nephropathy Study suggested that higher A1C-SD was significantly associated with increased risk of incident CVD. Both studies included patients with type 1 diabetes with a mean age of 37 years, a mean diabetes duration of 23 years, and a mean A1C of 8.0% (64 mmol/mol) (97,98). However, other studies among older individuals with type 1 diabetes (mean age 47–51 years, mean diabetes duration 27–40 years) did not find a significant association between A1C-CV or A1C-SD and incident stroke or CVD (99,100).

#### Metabolic Syndrome and Insulin Resistance

The metabolic syndrome may increase the risk of stroke even in euglycemic persons (101). The metabolic syndrome is a constellation of clinical and metabolic components, including elevated blood pressure and blood glucose, low high-density lipoprotein (HDL) cholesterol and high triglycerides as separate components, and abdominal obesity (102). Each component of the metabolic syndrome is individually recognized as a risk factor for stroke, but due to a synergistic relationship among these components, the collective entity of the metabolic syndrome is hypothesized to provide more accurate stroke risk estimates (103,104).

The metabolic syndrome was initially defined for use in persons without diabetes. Later research examined its potential role as an independent risk factor for diabetes complications, with some evidence supporting its association with incident stroke among persons with type 2 diabetes (105,106). For example, among 2,097 participants of the Framingham Offspring Study (1988–1990) who were age 50–81 years (mean 59.1 years) and free of stroke at baseline, risk ratios of stroke were estimated for men and women with metabolic syndrome alone, type 2 diabetes alone, and both, adjusting for age and standard stroke risk factors. In persons with both diabetes and metabolic syndrome, risk of stroke was higher than that for either condition alone (105). Compared to those without both conditions, those with both conditions had a risk ratio of 3.28 (95% CI 1.82–5.92); those with metabolic syndrome alone had a risk ratio of 2.10 (95% CI 1.37–3.22); and those with diabetes alone had a risk ratio of 2.47 (95% CI 1.31–4.65) (105). In the United Kingdom Prospective Diabetes Study (UKPDS), which included 4,542 subjects with newly diagnosed type 2 diabetes (age 25–65 years, mean age 52.5 years) and baseline data available for diagnosing metabolic syndrome between 1977 and 1991, the prevalence of metabolic syndrome varied by different definitions (23.8%–60.8%) (106). Over a median follow-up of 10 years, participants with both diabetes and metabolic syndrome had a higher risk of incident stroke compared to those with diabetes but without metabolic syndrome, with unadjusted risk ratios ranging from 1.4 to 1.7, depending on what definition of metabolic syndrome was applied in the analysis (106).

However, in other studies conducted among patients with or without diabetes, no evidence between metabolic syndrome and risk of stroke has been found (107,108,109). For example, among 44,548 REduction of Atherothrombosis for Continued Health (REACH) registry participants (2004–2005) with a mean age of 68 years, diabetes status at baseline was categorized as established diabetes (self-reported history of diabetes or use of diabetes drugs), newly detected diabetes (no history and not previously on treatment, but baseline FPG ≥126 mg/dL), and no diabetes (109). In the final model adjusting for age and standard stroke risk factors, the authors found that after up to 4 years of follow-up, compared to those with neither metabolic syndrome nor diabetes (new or established), those with both conditions had similar increased risk of stroke (adjusted HR 1.23, 95% CI 1.06–1.42) as those with established diabetes alone (adjusted HR 1.28, 95% CI 1.12–1.47); those with metabolic syndrome alone had an HR of 0.96 (95% CI 0.84–1.11) for stroke; and those with newly detected diabetes with or without metabolic syndrome had an HR of 1.06 (95% CI 0.75–1.50). When comparing patients with both conditions to those with established diabetes alone (adjusted HR 0.98, 95% CI 0.90–1.07, p=0.72), no significant difference in risk of stroke for these two groups was found. Differences in the findings of the impact of metabolic syndrome on stroke risk in those with diabetes may be due to differences in age and/or baseline stroke risk.

The association between metabolic syndrome and CVD complications among individuals with type 1 diabetes has not been consistent, with some studies reporting metabolic syndrome as an independent and significant predictor of CVD (110,111,112,113), while results from the DCCT/EDIC and Pittsburgh EDC reported no significant association (114,115). This discrepancy may be due to the small sample sizes of the studies (n=1,337 for DCCT/EDIC and n=514 for Pittsburgh EDC) and the young age of the study populations (mean age 27 years). In general, data with stroke as an outcome among persons with type 1 diabetes are lacking.

The metabolic syndrome is typically a reflection of insulin resistance, present in most persons with type 2 diabetes. While insulin resistance can be assessed by several methods, and fasting insulin is a reasonable reflection of insulin resistance in persons without diabetes, the homeostasis model assessment of insulin resistance (HOMA-IR) is the most commonly used measure of insulin resistance in epidemiologic studies (116,117). Other indicators to measure insulin resistance include the triglyceride-glucose (TyG) index and the estimated glucose disposal rate (eGDR), which was originally developed among patients with type 1 diabetes, with higher values representing more severe insulin resistance. Literature reporting insulin resistance as a predictor of incident stroke among individuals with diabetes is limited, partially due to the fact that fasting insulin and HOMA-IR are not reliable reflections of insulin resistance in persons with diabetes compared to persons without diabetes. In addition, HOMA-IR cannot be used as a measure of insulin resistance in patients with type 1 diabetes who receive exogenous insulin.

The association between HOMA-IR and risk of stroke or CVD among persons with type 2 diabetes remains unclear. Several studies have reported that an increased level of HOMA-IR was associated with an increased risk of CVD among persons with prevalent type 2 diabetes (118,119,120,121), but research conducted among patients with newly diagnosed type 2 diabetes, including one study from the UKPDS (122), has not found a significant association.

Current evidence, mostly among patients with type 2 diabetes with or without other comorbidities, such as acute coronary syndrome, who were recruited from hospitals in China (123,124,125,126,127), supports the TyG index as a predictor of CVD (123,124,125,126,127,128,129,130,131); however, there are no firm conclusions for stroke (125,126,127,128,129,130,131). A nationwide study of 208,865 persons with diagnosed type 2 diabetes from South Korea found HRs of 1.25 (95% CI 1.18–1.33) for stroke and 1.19 (95% CI 1.10–1.28) for myocardial infarction (MI) for those in the highest compared with the lowest TyG index quartile (128). Although similar associations for MI were observed in the post-hoc analysis of the Action to Control Cardiovascular Risk in Diabetes (ACCORD) trial (130) and other research (125,126,127,128,129,130), only some of these studies reported a significant association or a trend towards significant association between the TyG index and risk of nonfatal stroke (125,126,127,128,129,130,131). Of note, the numbers of nonfatal MI were larger than those for nonfatal stroke, which ranged from 16 to 485 (126,127,129,130).

Compared to evidence for the TyG index, very few studies have investigated the association between eGDR and risk of stroke among persons with type 2 diabetes. Among the few existing studies, a significant inverse association was found (132,133,134). Among persons with type 1 diabetes, a meta-analysis that included 19,960 individuals from five cohort studies reported that the pooled HR for a composite CVD outcome for a 10-unit increase in the eGDR index (lower level of insulin resistance) was 0.83 (95% CI 0.78–0.90) (135); no studies have specifically reported the association of eGDR with incident stroke.

#### Albuminuria

As a marker of renal function, albuminuria is measured by the urine albumin:creatinine ratio (UACR). Many studies have demonstrated that the absolute level of the UACR is a predictor of stroke or CVD among persons with type 2 diabetes, with or without CVD comorbidities, independent of estimated glomerular filtration rate (eGFR) and other CVD risk factors (136,137,138,139,140,141,142,143); however, the independent contributions of albuminuria to CVD risk appear small (141). Changes in albuminuria may also predict risk of CVD among persons with type 2 diabetes, independent of absolute level of albuminuria (144,145,146,147). Studies examining the association among individuals with type 1 diabetes are scarce (148,149,150), but all reported moderate to severe albuminuria as a predictor of incident CVD.

#### Diabetic Retinal Disease

A systematic review and meta-analysis, including nine cohort studies and randomized controlled trials (RCTs) among individuals with type 2 diabetes, showed that the presence of any diabetic retinopathy was associated with increased risks of total stroke (pooled adjusted HR 1.29, 95% CI 1.10–1.50) and ischemic stroke (pooled adjusted HR 1.19, 95% CI 1.04–1.36) (151). One study considered the subtypes of ischemic stroke and reported that any diabetic retinopathy was associated with small artery ischemic stroke but not with large artery ischemic stroke (12). Three studies examined the association with hemorrhagic stroke, with two studies reporting no association (12,152) and one from UK Biobank reporting a statistically significant positive association (adjusted HR 1.55, 95% CI 1.17–2.06) (153). The systematic review also found that severity of diabetic retinopathy was associated with an increased risk of stroke (pooled adjusted HR 2.08, 95% CI 1.44–2.99, comparing patients with moderate to severe nonproliferative or proliferative retinopathy to those with mild nonproliferative retinopathy or no retinopathy) (151). Another meta-analysis, including 7,604 patients with type 2 diabetes across eight population-based studies, showed that diabetic macular edema was associated with increased risk of CVD, including stroke (154); data for risk of total stroke and stroke subtypes were not specifically presented due to the small number of strokes within the pooled cohorts.

Research investigating the association between stroke and diabetic retinopathy among individuals with type 1 diabetes has been scarce. In the Wisconsin Epidemiologic Study of Diabetic Retinopathy, the positive association between severe retinopathy and 20-year risk of stroke became statistically insignificant after adjusting for diabetic nephropathy (41). However, in 1,268 adults with type 1 diabetes in the FinnDiane Study (mean age 38.7 ± 11.8 years, mean duration of diabetes 25.5 ± 9.7 years) (155), nonproliferative retinopathy and proliferative retinopathy were both associated with increased risk of stroke in the same magnitude after a median of 18.0 (95% CI 14.1–19.3) follow-up years, independent of diabetic kidney disease and other standard risk factors. The study also found that severity of retinopathy was associated with increased risks of ischemic and hemorrhagic stroke, but this was not independent of diabetic kidney disease (155). Similarly, the positive association between macular edema and incident stroke became statistically insignificant after adjusting for diabetic nephropathy (155).

### Other Predictors of Stroke Risk

#### Biomarkers for Emerging Proteomic Risk Factors

Numerous studies have investigated the associations of cardiovascular risk in type 2 diabetes with single biomarkers of known pathophysiological pathways, including those related to cardiac stress (N-terminal prohormone of b-type natriuretic peptide [NT-proBNP] (156,157,158) and high-sensitivity troponin T [hsTnT] (157,158)), inflammation (high-sensitivity C-reactive protein [CRP] (158,159,160,161), interleukin [IL]-6 (162), IL-18 (163), angiopoietin-like 2 (164), and tenascin-C (165)), and AGEs and their receptors (166,167,168,169,170,171,172). These biomarkers alone may lead to modest improvements in the prediction of CVD or stroke in diabetes beyond standard risk factors.

Recent studies have focused on evaluating the role of large numbers of biomarkers simultaneously in improving CVD prediction (173,174,175,176,177). For example, one study evaluated 80 inflammatory proteins measured in six prospective studies among individuals with type 2 diabetes and found that the addition of the 80-protein assay improved the prediction of cardiovascular events beyond traditional risk factors, with C-statistics improving from 0.686 (95% CI 0.682–0.689) to 0.748 (95% CI 0.746–0.751) (176). The study also identified eight protein biomarkers that were associated with risk of CVD independent of standard risk factors: matrix metalloproteinase (MMP)-12, IL-27 subunit α (IL-27a), kidney injury molecule (KIM)-1, fibroblast growth factor (FGF)-23, protein S100-A12, tumor necrosis factor (TNF) receptor (TNFR)-1, TNFR-2, and TNF-related apoptosis-inducing ligand receptor (TRAIL-R) 2; however, the combination of these eight markers did not improve the risk prediction (176). In another study that evaluated 42 candidate biomarkers from multiple physiological pathways in individuals with type 2 diabetes (174), the authors identified six biomarkers that in combination improved CVD prediction beyond standard risk factors: NT-proBNP, hsTnT, IL-6, IL-15, apolipoprotein C-III, and soluble receptor for AGE.

Among persons with type 1 diabetes, few relevant studies have been published, but existing studies showed a significant independent association between CRP (178,179), IL-6, TNF-α, and adiponectin (179,180), and AGEs (181,182) as independent predictors of incident CVD, while data from 886 DCCT/EDIC participants did not support an association of CRP or IL-6 with subclinical atherosclerosis (183).

#### Obstructive Sleep Apnea (OSA)

Evidence on an association between OSA and risk of stroke or CVD among persons with type 2 diabetes is inconclusive, with some studies reporting a positive and independent association (184,185,186,187,188,189,190) and others finding no association (191,192). Most studies have been cross-sectional (188,191) or cohort studies with small sample sizes between 248 and 1,447 (185,186,187,189,192). One large prospective cohort study, based on the U.K. primary care database, compared 3,677 persons with type 2 diabetes and incident diagnosed OSA to 10,450 matched persons with type 2 diabetes and no OSA; the adjusted HR for incident stroke/TIA was 1.57 (95% CI 1.27–1.94) (190).

Observational studies examining the association between OSA and risk of stroke or CVD among persons with type 1 diabetes are rare. Two cross-sectional studies reported that OSA, defined by oxygen desaturation index ≥15 events/hour or apnea-hypopnea index >10/hour, was significantly associated with prevalence of CVD or stroke among French persons with type 1 diabetes (193,194).

#### Autonomic Neuropathy

Cardiac autonomic neuropathy (CAN) is the impairment of autonomic nerves in the parasympathetic and sympathetic nervous systems (195). The gold standard to measure CAN is CVD autonomic reflex tests, but heart rate variability time-domain indices are commonly used in large-scale studies (195). The presence, severity, and progression of CAN are independently associated with increased risk of stroke (26,196,197) or CVD (26,196,197,198,199,200,201,202) among persons with both type 1 and type 2 diabetes. In research based on ACCORD (197), among 3,493 persons (mean age 62.2 years, 44.5% women, 62.9% White) with type 2 diabetes, 50 strokes occurred over a median follow-up of 5.0 years. The authors found that low heart rate variability was associated with a two times higher risk of stroke after adjusting for confounders (197). Among 1,441 persons with type 1 diabetes recruited in the DCCT/EDIC studies, 299 participants developed CVD during follow-up; the presence of CAN measured by reflex testing remained marginally significantly associated with increased risk of CVD after adjusting for standard CVD risk factors (199).

## Glycemic Control for Primary Stroke Prevention

As described above, epidemiologic studies have demonstrated an association between hyperglycemia and the risk of stroke and other CVD events (2,203,204). Preclinical models have also demonstrated a direct effect of hyperglycemia on endothelial dysfunction and atherosclerotic lesion formation (205). Yet, several large clinical trials of intensive glycemic control have failed to show a clear reduction in stroke or CVD event risk. Results from these trials are briefly summarized (Tables 9 and 10).

The first large trial to evaluate intensive glycemic control was the UKPDS (206). This trial randomized 3,867 patients with newly diagnosed type 2 diabetes to an intensive treatment arm using insulin or a sulfonylurea agent for glycemic control or to a conventional treatment arm consisting of dietary modifications. The mean age at enrollment was 53 years. Those randomized to the intensive treatment group achieved an A1C of 7.0% over a 10-year period compared to 7.9% in the conventional therapy group. There was no difference between the groups in risk of stroke or other CVD events at the conclusion of the trial. In a UKPDS substudy, intensive treatment with metformin led to a reduction in stroke risk compared to treatment with sulfonylureas or insulin (despite no difference in glycemic control), although there was no difference in stroke risk in the metformin group compared to conventional treatment (207). After an additional 8–9 years of post-trial follow-up, those who had received intensive compared to conventional treatment had lower rates of MI and all-cause mortality, but there was no statistical difference in stroke rates (208).

ACCORD randomized 10,251 individuals with longstanding type 2 diabetes and A1C ≥7.5% (≥58 mmol/mol) who were at high risk for CVD to either intensive therapy targeting a A1C of <6% or standard therapy targeting a A1C of 7.0%–7.9% (53–63 mmol/mol) (209). The median age at enrollment was 62 years and median A1C was 8.1% (65 mmol/mol). Over a mean follow-up duration of 3.5 years, the intensive treatment group achieved a mean A1C of 6.4% compared to 7.5% in the standard therapy group. The trial was stopped early due to a statistically significant increase in all-cause mortality among patients in the intensive treatment group (5% vs. 4%, p=0.04). There was no difference in the rate of nonfatal stroke between the two groups.

The Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified-Release Controlled Evaluation (ADVANCE) trial (210) was published simultaneously with ACCORD. ADVANCE randomized 11,140 individuals with longstanding type 2 diabetes to an intensive treatment group that included use of the sulfonylurea agent gliclazide plus other medications as needed to achieve a A1C of ≤6.5% or to a standard glucose control group. The mean age at enrollment was 66 years and mean A1C was 7.5%. Over a median follow-up duration of 5 years, the intensive control group achieved lower mean A1C levels (6.5%) than the standard treatment group (7.3% [56 mmol/mol]). There was no statistical difference in the rate of CVD events, including stroke, and no difference in all-cause mortality. Severe hypoglycemia events occurred more frequently in the intensive treatment group.

The Veterans Affairs Diabetes Trial (VADT) randomized 1,791 military veterans with longstanding type 2 diabetes to an intensive therapy group with a goal of 1.5% reduction in A1C or to a standard treatment group (211). The mean age at enrollment was 60 years, and the mean A1C was 9.5% (80 mmol/mol). Over a median follow-up of 5.6 years, the intensive treatment group achieved a median A1C of 6.9% (52 mmol/mol) compared to 8.4% (68 mmol/mol) in the standard treatment group. There was no difference in the risk of stroke, CVD events, or all-cause mortality.

The DCCT evaluated intensive glycemic control among younger patients with type 1 diabetes (212). A total of 1,441 patients with a median age of 27 years at enrollment were randomized to conventional therapy or intensive insulin therapy with a goal A1C of ≤6%. At the conclusion of the DCCT, 1,394 participants agreed to join EDIC and were followed longitudinally to ascertain CVD outcomes (213). By the end of the DCCT, the intensive treatment group had achieved a lower A1C than the conventional treatment group (7.4% vs. 9.1% [57 vs. 76 mmol/mol]). At the end of the 17-year follow-up period, those who had been in the intensive treatment group had a risk reduction of 42% for any CVD event. There were numerically fewer strokes in the intensive treatment group compared to the conventional treatment group (1 vs. 5 strokes), although this difference was not statistically significant.

### Specific Glycemic Control Agents for Stroke Prevention Among Patients With Type 2 Diabetes

While trials of intensive glycemic control strategies have failed to show a clear reduction in stroke risk (albeit with acceptable control in the control groups of ACCORD and ADVANCE), several trials of specific glycemic control agents have demonstrated a reduction in stroke and CVD event risk. In many cases, benefit was demonstrated with respect to a composite outcome that included strokes and was not present when strokes were analyzed separately. In some cases, a benefit with respect to stroke risk reduction specifically was demonstrated. Results from these trials are briefly summarized.

The PROactive (PROspective pioglitAzone Clinical Trial In macroVascular Events) Study randomized 5,238 patients with type 2 diabetes and evidence of macrovascular disease to receive the thiazolidinedione agent pioglitazone or placebo, in addition to standard care (214). The mean age at enrollment was 62 years, median A1C was 7.9%, and 19% had a history of stroke. Over an average follow-up of 34.5 months, patients in the pioglitazone group achieved a mean reduction of 1.1% in A1C compared to 0.3% in the placebo arm. Those in the pioglitazone arm had lower risk of a composite endpoint of all-cause mortality, nonfatal MI, and nonfatal stroke. In a prespecified subgroup analysis including the 984 patients with previous stroke at trial entry, pioglitazone led to a significant reduction in stroke risk (HR 0.53, event rate 5.6% pioglitazone vs. 10.2% placebo, 95% CI 0.34–0.85) (215).

The Insulin Resistance Intervention after Stroke Trial (IRIS) evaluated the effectiveness of pioglitazone in preventing recurrent CVD events in patients with recent stroke or TIA who had insulin resistance but not diabetes (216). A total of 3,876 patients were randomized to pioglitazone or placebo in addition to standard care. Pioglitazone led to a significantly lower risk of the primary composite outcome of fatal or nonfatal stroke or MI (HR 0.76, event rate 9.0% pioglitazone vs. 11.8% placebo, 95% CI 0.62–0.93). There were numerically fewer strokes in the pioglitazone group, but this was not statistically significant.

The EMPA-REG OUTCOME (Empagliflozin Cardiovascular Outcome Event Trial in Type 2 Diabetes Mellitus Patients) trial randomized 7,020 patients with type 2 diabetes who were at high CVD risk to receive either empagliflozin (an inhibitor of the sodium-glucose cotransporter-2 [SGLT2]) or to receive placebo, in addition to standard care (217). Patients had a mean age of 63 years at enrollment, mean A1C of 8.1%, and 23% had a history of stroke. Those in the empagliflozin group maintained a reduction in mean A1C ranging from 0.60% to 0.24% relative to placebo over a median observation time of 3.1 years, along with small reductions in weight and blood pressure. Empagliflozin led to a 1.6% absolute risk reduction in the primary outcome of CVD mortality, nonfatal MI, or nonfatal stroke (HR 0.86, 95% CI 0.74–0.99). This outcome was driven primarily by a reduction in CVD mortality, with no statistical difference in nonfatal stroke or MI between the groups, although there was a numerically higher stroke rate in the empagliflozin group.

The Canagliflozin Cardiovascular Assessment Study (CANVAS) was a trial of the SGLT2 inhibitor canagliflozin (218). A total of 10,142 participants with type 2 diabetes who were at high CVD risk were randomized to receive canagliflozin or placebo. The mean age was 63 years at trial entry, mean A1C was 8.2% (66 mmol/mol), and 19% had a history of cerebrovascular disease. Over a mean follow up of 3.6 years, canagliflozin led to a mean reduction in A1C of 0.6% compared to placebo, along with reductions in body weight and blood pressure. Those in the canagliflozin group had significantly lower risk of the primary composite outcome of CVD mortality, nonfatal MI, or nonfatal stroke (HR 0.86, 95% CI 0.75–0.97). There were numerically fewer strokes in the canagliflozin group, although this was not statistically significant.

The LEADER (Liraglutide Effect and Action in Diabetes: Evaluation of Cardiovascular Outcome Results) trial randomized 9,340 patients with type 2 diabetes and high CVD risk to receive the glucagon-like peptide-1 (GLP-1) analogue liraglutide or placebo, in addition to standard care (219). The mean age was 64 years at enrollment, mean A1C was 8.7% (72 mmol/mol), and 16% had a history of stroke or TIA. Those in the liraglutide group had a reduction in A1C of 0.4% compared to placebo at 36 months, along with small reductions in weight and systolic blood pressure, and small increases in heart rate and diastolic blood pressure. Over a median follow-up of 3.5 years, liraglutide led to a 1.9% absolute reduction in the primary composite outcome of CVD death, nonfatal MI, or nonfatal stroke (HR 0.87, 95% CI 0.78–0.97). There were numerically fewer strokes in the liraglutide group, though this was not statistically significant.

SUSTAIN-6 (Trial to Evaluate Cardiovascular and Other Long-term Outcomes with Semaglutide in Subjects with Type 2 Diabetes) randomized 3,297 patients with type 2 diabetes (83% of whom had established CVD and/or chronic kidney disease) to receive either the GLP-1 analogue semaglutide or placebo for 2 years (220). The mean age was 65 years at enrollment, mean A1C was 8.7%, and 14.9% had a history of stroke. At 2 years, the mean A1C values in semaglutide-treated patients were 0.7%–1.0% lower than in the placebo group. There were also reductions in body weight and blood pressure. Those in the semaglutide group had a 2.2% absolute risk reduction in the primary composite outcome of CVD death, nonfatal MI, or nonfatal stroke (HR 0.74, 95% CI 0.58–0.95) and a statistically significant 1.1% absolute risk reduction in nonfatal stroke (HR 0.61, 95% CI 0.38–0.99).

The REWIND (Researching Cardiovascular Events with a Weekly Incretin in Diabetes) trial randomized 9,901 patients with type 2 diabetes at high CVD risk to receive either the GLP-1 analogue dulaglutide or placebo (221). The mean age was 66 years at enrollment, median A1C was 7.2% (55 mmol/mol), and 7% had a history of stroke. During follow-up, patients receiving dulaglutide had A1C values that were 0.6% lower compared to the placebo group, along with small reductions in weight and blood pressure. During a mean follow-up of 5.4 years, the dulaglutide group experienced a 1.4% absolute risk reduction in the primary composite outcome of CVD death, nonfatal MI, or nonfatal stroke (HR 0.88, 95% CI 0.79–0.99) and a statistically significant 0.8% absolute risk reduction in nonfatal stroke (HR 0.76, 95% CI 0.61–0.95).

In summary, intensive glycemic control strategies do not clearly reduce the risk of stroke or CVD events in patients with longstanding type 2 diabetes compared to moderate glycemic control and may led to increased mortality, as shown in one trial (209). In patients with newly diagnosed type 2 diabetes, there may be long-term benefits of intensive glycemic control with respect to MI and all-cause mortality as suggested by post-trial follow-up of UKPDS patients, although no clear reduction in stroke risk has been demonstrated (208). Similar long-term benefits may be present for patients with type 1 diabetes as suggested by DCCT/EDIC, although again no clear reduction in stroke risk has been demonstrated (213). In contrast to intensive glycemic control strategies, several specific glycemic control agents, including the GLP-1 analogues semaglutide and dulaglutide, reduce stroke risk among high-risk patients with type 2 diabetes (220,221). Among patients with type 2 diabetes and previous stroke, the thiazolidinedione agent pioglitazone reduces the risk of recurrent stroke (215). In addition, several agents, including the SGLT2 inhibitors empagliflozin and canagliflozin and the GLP-1 analogue liraglutide, reduce the risk of composite outcomes that include stroke, along with MI and CVD mortality, among high-risk patients with type 2 diabetes; these agents have not been shown to reduce the risk of stroke specifically. Notably, the cardiovascular outcomes trials evaluating GLP-1 analogues and SGLT2 inhibitors and the pioglitazone trials enrolled populations with higher baseline risk of stroke compared to earlier trials of intensive glycemic control, perhaps allowing greater power to detect a benefit, if present.

## Control of Other Stroke Risk Factors in Diabetes

Based on the American Heart Association (AHA)/American Stroke Association (ASA) and American Diabetes Association (ADA) guidelines, recommendations for control of vascular risk factors for primary and secondary stroke prevention are presented in Table 11 (222,223,224,225,226,227). Clinical trial outcomes for primary and secondary stroke prevention in persons with diabetes are summarized in Tables 9 and 10, respectively (143,206,209,210,211,212,216,220,221,228,229,230,231,232,233).

### Hypertension and Systolic Blood Pressure

Hypertension, especially systolic hypertension, is a major risk factor for stroke in both diabetic and nondiabetic populations, and it is the most frequently targeted modifiable factor for stroke prevention (1,14,222). Appropriate management of blood pressure is a cornerstone for prevention in all individuals; specifically, hypertension is common and has a high attributable risk for stroke (25%–50%), and numerous clinical trials and observational studies have shown that blood pressure-lowering therapy can reduce the risks of first and recurrent stroke (234). Most evidence supporting intervention strategies to reduce the risk of CVD in diabetes comes from trials of people with type 2 diabetes, and hence, the recommendations for CVD risk factor modification, such as hypertension control for reducing the risk of stroke, for people with type 1 diabetes are extrapolated from data obtained in people with type 2 diabetes and are similar to those for people with type 2 diabetes (222).

In UKPDS participants with type 2 diabetes and hypertension, a policy of tight blood pressure control compared to less tight blood pressure control showed that a 10 mmHg reduction in systolic blood pressure resulted in a significant 44% reduction in risk of fatal or nonfatal stroke (235). The 10-year observational follow-up study of the UKPDS blood pressure intervention trial showed that differences in blood pressure between the two groups disappeared within 2 years after termination of the trial, and the decrease in risk of fatal or nonfatal stroke diminished over time, dropping to a nonsignificant 23% reduction during the post-trial follow-up period (236). A prospective observational analysis of the UKPDS data suggested that each 10 mmHg reduction in the updated mean systolic blood pressure was associated with a significant 19% reduction in risk of fatal or nonfatal stroke (229).

RCTs have demonstrated that more intensive blood pressure reduction, if tolerated, is better for prevention of CVD, including stroke. Several meta-analyses of RCTs have specifically demonstrated a stroke prevention benefit down to a target systolic blood pressure of <130 mmHg or even <120 mmHg (222,234). A meta-analysis of five trials including 8,333 people with diabetes showed that compared to less tight blood pressure control, tighter blood pressure control for reduction in systolic blood pressure to <130 mmHg significantly reduced the risk of stroke by 39% (237). A meta-analysis of nine trials enrolling 11,005 participants with type 2 diabetes reported that intensive blood pressure lowering with a post-treatment blood pressure of <130/80 mmHg (~125/73 mmHg) resulted in a significant reduction in risk of any stroke by 36%, nonfatal stroke by 39%, and fatal stroke by 59% (238). Another network meta-analysis of 20 trials enrolling 42,877 patients with type 2 diabetes reported that the lowest risk of fatal or nonfatal stroke was found in those with an achieved systolic blood pressure of 120–124 mmHg, which showed a significant reduction in risk of any stroke of 58% compared to 125–129 mmHg, 81% compared to 130–134 mmHg, 82% compared to 135–139 mmHg, 85% compared to 140–144 mmHg, 89% compared to 145–149 mmHg, and 91% compared to ≥150 mmHg (239). Furthermore, the ACCORD-blood pressure (ACCORD-BP) trial of participants with type 2 diabetes revealed that intensive therapy targeting a systolic blood pressure <120 mmHg compared to standard therapy targeting a systolic blood pressure <140 mmHg resulted in a significant 41% reduction in risk of fatal or nonfatal stroke (240). More recently, the Blood Pressure Control Target in Diabetes (BPROAD) trial that enrolled patients with type 2 diabetes, elevated systolic blood pressure, and an increased risk of CVD showed that intensive treatment targeting a systolic blood pressure <120 mmHg compared to standard treatment targeting a systolic blood pressure <140 mmHg resulted in a significant 21% reduction in risk of fatal or nonfatal stroke (241).

The 2025 ADA Standards of Care in Diabetes recommend that for people with diabetes and hypertension, blood pressure goals should be individualized through a shared decision-making process that addresses CVD risk, potential adverse effects of antihypertensive medications, and individual preferences (222). The on-treatment blood pressure goal for people with diabetes who have hypertension is <130/80 mmHg, if it can be safely attained (222). In individuals with confirmed office-based blood pressure ≥130/80 mmHg, pharmacologic therapy should be initiated and titrated to achieve the recommended blood pressure goal of <130/80 mmHg. Individuals with confirmed office-based blood pressure ≥150/90 mmHg should, in addition to lifestyle therapy, have prompt initiation and timely titration of two drugs or a single-pill combination of drugs demonstrated to reduce CVD events in people with diabetes. Treatment for hypertension should include any of the drug classes demonstrated to reduce CVD events in people with diabetes, including angiotensin-converting enzyme (ACE) inhibitors, angiotensin receptor blockers (ARBs), thiazide-like diuretics, or dihydropyridine calcium channel blockers. ACE inhibitors or ARBs, if there are no contraindications, are recommended first-line therapy for hypertension in people with diabetes, especially those with albuminuria or coronary artery disease (CAD). Monitoring is recommended for increased serum creatinine and serum potassium levels when ACE inhibitors, ARBs, and mineralocorticoid receptor antagonists are used, and for hypokalemia when diuretics are used, at routine clinic visits and 7–14 days after initiation or after a dose change.

### Lifestyle Interventions

Lifestyle choices play a crucial role in stroke prevention, particularly through the management of hypertension, the strongest modifiable risk factor for stroke. For people with diabetes, the 2025 ADA guidelines recommend lifestyle modifications focusing on weight loss (if indicated), application of healthy diet habits, and increased physical activity to maintain or achieve blood pressure, lipid, and glucose control (222). Youth with type 1 diabetes or type 2 diabetes are recommended to engage in 60 minutes per day or more of moderate- or vigorous-intensity aerobic activity, with muscle-strengthening and bone-strengthening activities at least three days per week. Adults with type 1 diabetes and type 2 diabetes are recommended to engage in 150 minutes or more of moderate- to vigorous-intensity aerobic activity per week, spread over at least three days per week, with no more than two consecutive days without activity.

### Dyslipidemia

Both type 1 diabetes and type 2 diabetes are associated with dyslipidemia (242,243,244). In the UKPDS, a 1-unit increase in lipid ratio total:HDL cholesterol was associated with a 14% higher stroke risk in adults with type 2 diabetes (245). The Collaborative Atorvastatin Diabetes Study (CARDS) of 2,838 diabetes patients (99.9% type 2 diabetes) showed that atorvastatin 10 mg per day was associated with a 48% reduction in stroke risk compared to placebo (246). Subsequent results from an individual-level data meta-analysis of 1,466 type 1 diabetes and 17,220 type 2 diabetes patients in 14 RCTs showed that a 1 mmol/L (39 mg/dL) reduction in serum low-density lipoprotein (LDL) cholesterol was associated with a 21% (95% CI 7%–33%) reduction in stroke risk (247). A more recent meta-analysis found that statin use significantly reduced the risk of ischemic stroke in patients with diabetes, with a risk ratio of 0.83 (95% CI 0.70–0.97) for primary prevention based on pooled data from four RCTs and a risk ratio of 0.74 (95% CI 0.63–0.85) for secondary prevention based on pooled data from five RCTs (248).

ADA guidelines recommend moderate-intensity statin therapy for people with diabetes age 40–75 years without known atherosclerotic CVD (ASCVD) and high-intensity statin therapy for people with diabetes age 40–75 years at higher cardiovascular risk, including those with one or more additional ASCVD risk factors (222).

### Antiplatelet and Anticoagulant Use

Previous RCTs failed to show a consistent effect of aspirin to prevent the first stroke in individuals with diabetes. In a meta-analysis of 13 trials with 164,225 participants without CVD, aspirin use was associated with a significant reduction in nonfatal stroke (HR 0.89, absolute risk reduction 0.41%) and an increased risk of major bleeding (HR 1.43, absolute risk increase 0.47%) but was not associated with risk of total stroke (HR 0.93, 95% CI 0.86–1.02) (249).

The ASCEND (A Study of Cardiovascular Events in Diabetes) trial concluded that aspirin use prevented serious vascular events in persons who had diabetes and no evident CVD at trial entry, but it also caused major bleeding events (250). The JPAD (Japanese Primary Prevention of Atherosclerosis With Aspirin for Diabetes) trial showed that low-dose aspirin did not affect the risk for CVD events but increased risk for gastrointestinal bleeding in patients with type 2 diabetes in a primary prevention setting (251). In individuals age ≥70 years with at least one additional CVD risk factor or patients with chronic kidney disease, the use of aspirin is not beneficial to prevent a first stroke (252).

In individuals with AF, the CHA2DS2-VASc score is recommended to inform risk-based anticoagulation of patients with nonvalvular AF of any duration. However, the CHA2DS2-VASc instrument is imperfect in that risk of stroke varies among populations with the same score. For this reason, the AHA, ASA, and American College of Cardiology (ACC) all emphasize that treatment decisions should be individualized in the context of shared decision-making and both stroke and bleeding risk should be taken into consideration (223).

In patients with noncardioembolic ischemic stroke or TIA, antiplatelet therapy is indicated in preference to oral anticoagulation to reduce the risk of recurrent ischemic stroke and other CVD events while minimizing the risk of bleeding (253,254).

In patients with ischemic stroke or TIA and left atrial or right atrial appendage thrombus in the setting of ischemic, nonischemic, or restrictive cardiomyopathy and left ventricular (LV) dysfunction, or Fontan palliation, anticoagulant therapy with warfarin is recommended to reduce the risk of recurrent stroke or TIA. In patients with nonvalvular AF or atrial flutter and stroke or TIA, oral anticoagulation (e.g., apixaban, dabigatran, edoxaban, rivaroxaban, or warfarin) is recommended to reduce the risk of recurrent stroke (223).

### Carotid Artery Disease

Extracranial carotid artery stenosis is common among individuals with diabetes and is associated with increased risk of stroke. Screening in the general population is not recommended, but some consideration must be given to specific high-risk asymptomatic populations, such as those with atherosclerotic risk factors (hypertension, current tobacco use, CAD, or first-degree family member with a history of stroke).

The Asymptomatic Carotid Atherosclerosis Study (ACAS) conducted between 1987 and 1993 highlighted the benefits of carotid revascularization (carotid endarterectomy [CEA] or transfemoral stenting). Over the past two decades, medical and interventional treatment for acute coronary syndrome to reduce the risk of stroke has evolved significantly (255); however, it is unclear whether revascularization offers additional benefit in asymptomatic patients who receive contemporary medical management. An ongoing trial, CREST-2 (Carotid Revascularization and Medical Management for Asymptomatic Carotid Stenosis), is expected to provide clarity on this subject (256).

The 2024 AHA/ASA guideline recommended optimal medical management, including high-intensity statin therapy, for all patients with asymptomatic carotid artery atherosclerosis (252). Duplex ultrasound every 6–12 months is recommended for screening patients with atherosclerotic carotid artery stenosis >50% to evaluate the severity and progression of disease. Due to lack of consensus, in patients with asymptomatic atherosclerotic carotid artery stenosis >70%, the guideline emphasized the importance of shared decision-making between the patient and the healthcare team to decide between the two courses of treatment (carotid revascularization or medical management).

CEA is considered beneficial for patients with recent symptomatic carotid territory nondisabling ischemic stroke or TIA and ipsilateral 50%–99% internal carotid artery stenosis. For preventing short-term recurrent stroke, CEA should be offered as soon as possible to these patients who are fit and willing to undergo surgery, ideally within the first few days and up to one week after the ischemic event (224). The rate of perioperative stroke or death with carotid artery stenting was as high as with CEA in patients age ≥70 years and might be as safe as CEA in patients age <70 years. Carotid stenting could also be considered for patients who are not candidates for CEA due to technical, anatomical, or medical reasons (224).

## Acute Stroke Treatment in Persons With Diabetes

Acute stroke treatment of patients with diabetes is similar to treatment in patients without diabetes. However, there are certain details that should be considered when approaching patients with diabetes who present with focal neurologic deficits suggesting acute stroke. Both hypoglycemia and hyperglycemia can cause focal neurologic symptoms that mimic acute stroke (257). Before thrombolytic therapy or mechanical thrombectomy commence, blood glucose levels must be checked and consideration for this frequent stroke mimic should be entertained. Blood glucose levels of <50 mg/dL (<2.8 mmol/L) or >400 mg/dL (>22.2 mmol/L) are contraindications for intravenous (IV) thrombolytic therapy unless glucose levels are first normalized with resulting persistent stroke symptoms. In the case of persistent symptoms with resolved hypoglycemia or hyperglycemia, guidelines suggest thrombolytic treatment may be reasonable (257). Of course, patients with high and low blood glucose levels may also have acute stroke, and at times it is difficult to determine whether glucose dysregulation or acute ischemia is responsible for the patient’s symptoms. In general, correcting the blood glucose usually leads to a rapid resolution of neurologic symptoms, but at times, this process can take a while. The use of hyperacute MRI with diffusion-weighted imaging (DWI) sequences and/or perfusion imaging may help to distinguish a metabolic condition from acute ischemia.

Some reports suggest that patients treated with IV rt-PA (recombinant tissue-type plasminogen activator) who had high glucose were at increased risk of rt-PA-related ICH (258). However, within the blood glucose parameters mentioned above (50–400 mg/dL), guidelines do not suggest withholding thrombolysis in patients with modestly increased glucose in whom there is confidence in a diagnosis of acute ischemic stroke. Therefore, acute stroke therapy should proceed as quickly as possible.

### Intensive Glycemic Control Immediately Following Acute Ischemic Stroke

Several reports suggest that patients with diabetes and high glucose have worse stroke outcomes compared with patients who are not diabetic and are normoglycemic (259). The pathophysiologic explanation for this observation is not clear, although one study found more cerebral edema in patients with elevated glucose levels (260).

The Stroke Hyperglycemia Insulin Network Effort (SHINE) trial enrolled patients who presented within 12 hours from onset of acute ischemic stroke and had elevated blood glucose levels at presentation (>110 mg/dL, if the patient had diabetes, or >150 mg/dL (>8.3 mmol/L), if the patient did not have diabetes) (261). Patients were randomized to receive intensive glycemic control, including the use of intravenous insulin to achieve a target blood glucose concentration of 80–130 mg/dL (4.4–7.2 mmol/L), or to receive subcutaneous insulin to achieve a target of 80–179 mg/dL (4.4–9.9 mmol/L), for up to 72 hours. The mean blood glucose level during treatment for the intensive control group was 118 mg/dL (6.6 mmol/L) compared to 179 mg/dL for the standard treatment group. The trial was stopped early for futility, finding no difference in 90-day functional outcomes or all-cause mortality between the groups. There were significantly more episodes of hypoglycemia in the intensive treatment group. A subsequent meta-analysis of 15 RCTs and more than 2,900 patients did not find an outcome difference between acute stroke patients treated with intensive compared with standard glucose control (259). However, studies continue to show that high glucose levels are associated with worse stroke outcomes. A post-hoc analysis of the Highly Effective Reperfusion using Multiple Endovascular deviceS (HERMES) study showed that appropriate patients treated with endovascular therapy benefited regardless of glucose levels, but patients with lower glucose had the best outcomes (262).

Current guidelines recommend close monitoring of blood glucose levels and treatment of hyperglycemia to achieve a target blood glucose of 140–180 mg/dL (7.8–10.0 mmol/L) in the 24 hours after acute ischemic stroke (257).

## Stroke Prognosis in Persons With Diabetes

In addition to being a risk factor for incident stroke, diabetes is associated with worse prognosis following stroke. In a 2021 meta-analysis of 27 cohort studies and RCTs, diabetes was significantly associated with stroke recurrence in persons with ischemic stroke (pooled HR 1.65, 95% CI 1.41–1.92) (3). Risk of recurrent ischemic stroke was also higher in those with diabetes compared with those without diabetes (HR 1.53, 95% CI 1.30–1.81). With regard to other outcomes following stroke, a 2019 review of studies of stroke inpatients found that most, but not all, of the studies reported that diabetes was associated with higher mortality and poorer neurological and functional outcomes, although meta-analyses were not conducted (263). In data from the Get With the Guidelines-Stroke Registry, which included 409,060 stroke patients age ≥65 years from across the United States, diabetes was associated with higher all-cause mortality (adjusted HR 1.24, 95% CI 1.23–1.25), higher all-cause hospital readmissions (adjusted HR 1.22, 95% CI 1.21–1.23), and ischemic stroke/TIA hospital readmissions (adjusted HR 1.18, 95% CI 1.16–1.20) (264).

Hyperglycemia in individuals with ischemic stroke has been associated with worse post-stroke outcomes in those with and without diabetes (3). In a meta-analysis of five studies including 2,565 ischemic stroke patients receiving thrombolysis, hyperglycemia at admission (defined as random blood glucose >140 mg/dL) was associated with higher all-cause mortality at 90 days (odds ratio [OR] 2.51, 95% CI 1.65–3.82), higher risk of symptomatic ICH (OR 1.80, 95% CI 1.30–2.50), and higher odds of poor clinical outcome defined as a Modified Rankin Score (MRS) of >2 at 90 days (OR 1.82, 95% CI 1.52–2.19) (265).

## Conclusions

Stroke remains a leading cause of death in the United States, and the prevalence of stroke is expected to rise over the coming decades due to the aging population. Individuals with diabetes have an increased risk for incident and recurrent stroke, particularly ischemic stroke, compared with those without diabetes, and the prevalence of diabetes is increasing worldwide. Population data on stroke prevalence among those with diabetes are available from several national surveys conducted in the United States. These data demonstrate higher prevalence of stroke with increasing age and no differences in prevalence by sex. Standard vascular risk factors and diabetes-specific risk factors, including hyperglycemia and glycemic variability, metabolic syndrome and insulin resistance, albuminuria, and diabetic retinal diseases, are associated with increased stroke risk among persons with diabetes.

Clinical guidelines for control of vascular risk factors in persons with diabetes were updated in 2025. The most effective strategy to prevent stroke among this population is to ensure optimal blood pressure control. To date, RCTs of intensive glycemic control have not demonstrated a reduction in stroke risk; however, specific glycemic control agents, including the GLP-1 analogues semaglutide and dulaglutide, have been shown to reduce stroke risk in high-risk persons with type 2 diabetes. Diabetes has also been associated with adverse post-stroke outcomes, although intensive glucose control following an acute ischemic stroke has not been shown to improve outcomes compared with standard glucose control. A patient-centered approach to diabetes treatment, including consideration of the risk of stroke, is recommended.

## List of Abbreviations

A1C: glycated hemoglobin
ACCORD: Action to Control Cardiovascular Risk in Diabetes
ACE: angiotensin-converting enzyme
ADA: American Diabetes Association
ADVANCE: Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified-Release Controlled Evaluation
AF: atrial fibrillation
AGE: advanced glycation end-product
AHA: American Heart Association
ARB: angiotensin receptor blocker
ARIC: Atherosclerosis Risk in Communities study
ASA: American Stroke Association
BRFSS: Behavioral Risk Factor Surveillance System
CAD: coronary artery disease
CAN: cardiac autonomic neuropathy
CCW: Chronic Conditions Warehouse
CEA: carotid endarterectomy
CI: confidence interval
CRP: C-reactive protein
CSVD: cerebral small vessel disease
CV: coefficient of variation
CVD: cardiovascular disease
DCCT: Diabetes Control and Complications Trial
EDC: Epidemiology Diabetes Complications study
EDIC: Epidemiology of Diabetes Intervention and Complications study
eGDR: estimated glucose disposal rate
FHS: Framingham Heart Study
FPG: fasting plasma glucose
GCNKSS: Greater Cincinnati/Northern Kentucky Stroke Study
GLP-1: glucagon-like peptide-1
HCUP: Healthcare Cost & Utilization Project
HDL: high-density lipoprotein
HOMA-IR: homeostasis model assessment of insulin resistance
HR: hazard ratio
hsTNT: high-sensitivity troponin T
ICD-10: International Classification of Diseases, Tenth Revision
ICH: intracerebral hemorrhage
IL: Interleukin
IRR: incidence rate ratio
IV: intravenous
MI: myocardial infarction
MRI: magnetic resonance imaging
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
NHS: Nurses’ Health Study
NIS: National (Nationwide) Inpatient Sample
NOMAS: Northern Manhattan Study
NT-proBNP: N-terminal prohormone of b-type natriuretic peptide
OR: odds ratio
OSA: obstructive sleep apnea
RCT: randomized controlled trial
REGARDS: REasons for Geographic and Racial Differences in Stroke
SD: standard deviation
SGLT2: sodium-glucose cotransporter-2
TIA: transient ischemic attack
TNF: tumor necrosis factor
TyG: triglyceride-glucose
UKPDS: United Kingdom Prospective Diabetes Study

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

(HDL or LDL) Cholesterol: mg/dL x 0.0259 = mmol/L

Glucose: mg/dL x 0.0555 = mmol/L

Triglycerides: mg/dL x 0.0113 = mmol/L

## Acknowledgment

This is an update of: Pikula A, Howard BV, Seshadri S. Stroke and Diabetes. Chapter 19 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p 19-1–19-23

## Article History

Received in final form on August 22, 2025.

## References

1 Martin SS, Aday AW, Allen NB, et al. 2025 Heart Disease and Stroke Statistics: A Report of US and Global Data From the American Heart Association. Circulation. 2025;151(8):e41-e660. doi:10.1161/CIR.0000000000001303 39866113
2 Emerging Risk Factors Collaboration, Sarwar N, Gao P, et al. Diabetes mellitus, fasting blood glucose concentration, and risk of vascular disease: a collaborative meta-analysis of 102 prospective studies. Lancet. 2010;375(9733):2215-2222. doi:10.1016/S0140-6736(10)60484-9 20609967
3 Zhang L, Li X, Wolfe CDA, O’Connell MDL, Wang Y. Diabetes as an independent risk factor for stroke recurrence in ischemic stroke patients: an updated meta-analysis. Neuroepidemiology. 2021;55(6):427-435. doi:10.1159/000519327 34673640
4 Pikula A, Howard B, Seshadri S. Stroke and diabetes. In: Cowie C, Casagrande S, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institute of Diabetes and Digestive and Kidney Diseases; 2018; 19-1–19-23:chap 19. https://www.ncbi.nlm.nih.gov/books/NBK567972/
5 Sacco RL, Kasner SE, Broderick JP, et al. An Updated Definition of Stroke for the 21st Century: a statement for healthcare professionals from the American Heart Association/American Stroke Association. Stroke. 2013;44(7):2064-2089. doi:10.1161/STR.0b013e318296aeca 23652265
6 Brainin M, Heiss W-D, eds. Textbook of Stroke Medicine. Cambridge University Press; 2019. https://www.cambridge.org/core/books/textbook-of-stroke-medicine/A66218B523F3A8F88F34FC9AAB24A826
7 Adams HP, Jr., Bendixen BH, Kappelle LJ, et al. Classification of subtype of acute ischemic stroke. Definitions for use in a multicenter clinical trial. TOAST. Trial of Org 10172 in Acute Stroke Treatment. Stroke. 1993;24(1):35-41. doi:10.1161/01.str.24.1.35 7678184
8 Ay H, Benner T, Arsava EM, et al. A computerized algorithm for etiologic classification of ischemic stroke: the Causative Classification of Stroke System. Stroke. 2007;38(11):2979-2984. doi:10.1161/STROKEAHA.107.490896 17901381
9 Chen S, Zeng L, Hu Z. Progressing haemorrhagic stroke: categories, causes, mechanisms and managements. J Neurol. 2014;261(11):2061-2078. doi:10.1007/s00415-014-7291-1 24595959
10 Kissela BM, Khoury J, Kleindorfer D, et al. Epidemiology of ischemic stroke in patients with diabetes: the Greater Cincinnati/Northern Kentucky Stroke Study. Diabetes Care. 2005;28(2):355-359. doi:10.2337/diacare.28.2.355 15677792
11 Chen R, Ovbiagele B, Feng W. Diabetes and stroke: epidemiology, pathophysiology, pharmaceuticals and outcomes. Am J Med Sci. 2016;351(4):380-386. doi:10.1016/j.amjms.2016.01.011 27079344
12 Hankey GJ, Anderson NE, Ting RD, et al. Rates and predictors of risk of stroke and its subtypes in diabetes: a prospective observational study. J Neurol Neurosurg Psychiatry. 2013;84(3):281-287. doi:10.1136/jnnp-2012-303365 23085934
13 Tuttolomondo A, Pinto A, Salemi G, et al. Diabetic and non-diabetic subjects with ischemic stroke: differences, subtype distribution and outcome. Nutr Metab Cardiovasc Dis. 2008;18(2):152-157. doi:10.1016/j.numecd.2007.02.003 17702553
14 Bell DSH, Goncalves E. Stroke in the patient with diabetes (part 1)— epidemiology, etiology, therapy and prognosis. Diabetes Res Clin Pract. 2020;164:108193. doi:10.1016/j.diabres.2020.108193 32442554
15 Janghorbani M, Hu FB, Willett WC, et al. Prospective study of type 1 and type 2 diabetes and risk of stroke subtypes: the Nurses’ Health Study. Diabetes Care. 2007;30(7):1730-1735. doi:10.2337/dc06-2363 17389335
16 Luitse MJ, Biessels GJ, Rutten GE, Kappelle LJ. Diabetes, hyperglycaemia, and acute ischaemic stroke. Lancet Neurol. 2012;11(3):261-271. doi:10.1016/S1474-4422(12)70005-4 22341034
17 Mosenzon O, Cheng AY, Rabinstein AA, Sacco S. Diabetes and stroke: what are the connections? J Stroke. 2023;25(1):26-38. doi:10.5853/jos.2022.02306 36592968
18 Beckman JA, Creager MA, Libby P. Diabetes and atherosclerosis: epidemiology, pathophysiology, and management. JAMA. 2002;287(19):2570-2581. doi:10.1001/jama.287.19.2570 12020339
19 Seyed Ahmadi S, Svensson AM, Pivodic A, Rosengren A, Lind M. Risk of atrial fibrillation in persons with type 2 diabetes and the excess risk in relation to glycaemic control and renal function: a Swedish cohort study. Cardiovasc Diabetol. 2020;19(1):9. doi:10.1186/s12933-019-0983-1 31954408
20 Bohne LJ, Johnson D, Rose RA, Wilton SB, Gillis AM. The association between diabetes mellitus and atrial fibrillation: clinical and mechanistic insights. Front Physiol. 2019;10:135. doi:10.3389/fphys.2019.00135 30863315
21 Kamel H, Healey JS. Cardioembolic stroke. Circ Res. 2017;120(3):514-526. doi:10.1161/CIRCRESAHA.116.308407 28154101
22 van Sloten TT, Sedaghat S, Carnethon MR, Launer LJ, Stehouwer CDA. Cerebral microvascular complications of type 2 diabetes: stroke, cognitive dysfunction, and depression. Lancet Diabetes Endocrinol. 2020;8(4):325-336. doi:10.1016/S2213-8587(19)30405-X 32135131
23 Meigs JB, D’Agostino RB, Sr., Nathan DM, Rifai N, Wilson PW, Framingham Offspring Study. Longitudinal association of glycemia and microalbuminuria: the Framingham Offspring Study. Diabetes Care. 2002;25(6):977-983. doi:10.2337/diacare.25.6.977 12032102
24 Lee M, Saver JL, Chang KH, Liao HW, Chang SC, Ovbiagele B. Impact of microalbuminuria on incident stroke: a meta-analysis. Stroke. 2010;41(11):2625-2631. doi:10.1161/STROKEAHA.110.581215 20930164
25 Lee M, Saver JL, Chang KH, Liao HW, Chang SC, Ovbiagele B. Low glomerular filtration rate and risk of stroke: meta-analysis. BMJ. 2010;341:c4249. doi:10.1136/bmj.c4249 20884696
26 Cohen JA, Estacio RO, Lundgren RA, Esler AL, Schrier RW. Diabetic autonomic neuropathy is associated with an increased incidence of strokes. Auton Neurosci. 2003;108(1-2):73-78. doi:10.1016/j.autneu.2003.07.001 14614967
27 Cellek S, Anderson PN, Foxwell NA. Nitrergic neurodegeneration in cerebral arteries of streptozotocin-induced diabetic rats: a new insight into diabetic stroke. Diabetes. 2005;54(1):212-219. doi:10.2337/diabetes.54.1.212 15616031
28 Karapanayiotides T, Piechowski-Jozwiak B, van Melle G, Bogousslavsky J, Devuyst G. Stroke patterns, etiology, and prognosis in patients with diabetes mellitus. Neurology. 2004;62(9):1558-1562. doi:10.1212/01.wnl.0000123252.55688.05 15136681
29 Palacio S, McClure LA, Benavente OR, Bazan C, 3rd, Pergola P, Hart RG. Lacunar strokes in patients with diabetes mellitus: risk factors, infarct location, and prognosis: the secondary prevention of small subcortical strokes study. Stroke. 2014;45(9):2689-2694. doi:10.1161/STROKEAHA.114.005018 25034716
30 Cui R, Iso H, Yamagishi K, et al. Diabetes mellitus and risk of stroke and its subtypes among Japanese: the Japan public health center study. Stroke. 2011;42(9):2611-2614. doi:10.1161/STROKEAHA.111.614313 21836098
31 Morsy EY, Rohoma KH, Ali SAM, Elhalawany SH. Comparison study of clinical presentation and risk factors for cerebrovascular stroke in diabetic versus nondiabetic patients. Egypt J Intern Med. 2022;34(1):78. doi:10.1186/s43162-022-00165-1
32 Subramanian G, Silva J, Silver FL, et al. Risk factors for posterior compared to anterior ischemic stroke: an observational study of the Registry of the Canadian Stroke Network. Neuroepidemiology. 2009;33(1):12-16. doi:10.1159/000209282 19299902
33 Kim JS, Nah HW, Park SM, et al. Risk factors and stroke mechanisms in atherosclerotic stroke: intracranial compared with extracranial and anterior compared with posterior circulation disease. Stroke. 2012;43(12):3313-3318. doi:10.1161/STROKEAHA.112.658500 23160885
34 Seshadri S, Beiser A, Kelly-Hayes M, et al. The lifetime risk of stroke: estimates from the Framingham Study. Stroke. 2006;37(2):345-350. doi:10.1161/01.STR.0000199613.38911.b2 16397184
35 Madsen TE, Ding L, Khoury JC, et al. Trends over time in stroke incidence by race in the Greater Cincinnati Northern Kentucky Stroke Study. Neurology. 2024;102(3):e208077. doi:10.1212/WNL.0000000000208077 38546235
36 Madsen TE, Khoury JC, Leppert M, et al. Temporal trends in stroke incidence over time by sex and age in the GCNKSS. Stroke. 2020;51(4):1070-1076. doi:10.1161/STROKEAHA.120.028910 32078459
37 Herman AL, Sheth KN, Williams OA, Johnston KC, Prabhakaran S, de Havenon A. Self-reported race as a social determinant of stroke risk in observational versus clinical trial datasets. J Stroke Cerebrovasc Dis. 2022;31(2):106219. doi:10.1016/j.jstrokecerebrovasdis.2021.106219 34826677
38 Gardener H, Sacco RL, Rundek T, Battistella V, Cheung YK, Elkind MSV. Race and ethnic disparities in stroke incidence in the Northern Manhattan Study. Stroke. 2020;51(4):1064-1069. doi:10.1161/STROKEAHA.119.028806 32078475
39 Muller CJ, Alonso A, Forster J, et al. Stroke incidence and survival in American Indians, Blacks, and Whites: the Strong Heart Study and Atherosclerosis Risk in Communities Study. J Am Heart Assoc. 2019;8(12):e010229. doi:10.1161/JAHA.118.010229 31189396
40 Malla G, Long DL, Judd SE, et al. Does the association of diabetes with stroke risk differ by age, race, and sex? Results from the REasons for Geographic and Racial Differences in Stroke (REGARDS) study. Diabetes Care. 2019;42(10):1966-1972. doi:10.2337/dc19-0442 31391199
41 Klein BE, Klein R, McBride PE, et al. Cardiovascular disease, mortality, and retinal microvascular characteristics in type 1 diabetes: Wisconsin Epidemiologic Study of Diabetic Retinopathy. Arch Intern Med. 2004;164(17):1917-1924. doi:10.1001/archinte.164.17.1917 15451768
42 Secrest AM, Prince CT, Costacou T, Miller RG, Orchard TJ. Predictors of and survival after incident stroke in type 1 diabetes. Diab Vasc Dis Res. 2013;10(1):3-10. doi:10.1177/1479164112441006 22535586
43 Roy MS, Peng B, Roy A. Risk factors for coronary disease and stroke in previously hospitalized African-Americans with type 1 diabetes: a 6-year follow-up. Diabet Med. 2007;24(12):1361-1368. doi:10.1111/j.1464-5491.2007.02293.x 17976202
44 Abbott RD, Donahue RP, MacMahon SW, Reed DM, Yano K. Diabetes and the risk of stroke. The Honolulu Heart Program. JAMA. 1987;257(7):949-952. doi:10.1001/jama.1987.03390070069025 3806877
45 Khoury JC, Kleindorfer D, Alwell K, et al. Diabetes mellitus: a risk factor for ischemic stroke in a large biracial population. Stroke. 2013;44(6):1500-1504. doi:10.1161/STROKEAHA.113.001318 23619130
46 Rodriguez BL, D’Agostino R, Abbott RD, et al. Risk of hospitalized stroke in men enrolled in the Honolulu Heart Program and the Framingham Study: a comparison of incidence and risk factor effects. Stroke. 2002;33(1):230-236. doi:10.1161/hs0102.101081 11779915
47 Zhang Y, Galloway JM, Welty TK, et al. Incidence and risk factors for stroke in American Indians: the Strong Heart Study. Circulation. 2008;118(15):1577-1584. doi:10.1161/CIRCULATIONAHA.108.772285 18809797
48 Huxley RR, Bell EJ, Lutsey PL, et al. A comparative analysis of risk factors for stroke in Blacks and Whites: the Atherosclerosis Risk in Communities study. Ethn Health. 2014;19(6):601-616. doi:10.1080/13557858.2013.857765 24261746
49 Ariesen MJ, Claus SP, Rinkel GJ, Algra A. Risk factors for intracerebral hemorrhage in the general population: a systematic review. Stroke. 2003;34(8):2060-2065. doi:10.1161/01.STR.0000080678.09344.8D 12843354
50 Tuszynski MH, Petito CK, Levy DE. Risk factors and clinical manifestations of pathologically verified lacunar infarctions. Stroke. 1989;20(8):990-999. doi:10.1161/01.str.20.8.990 2474207
51 Jackson C, Sudlow C. Are lacunar strokes really different? A systematic review of differences in risk factor profiles between lacunar and nonlacunar infarcts. Stroke. 2005;36(4):891-901. doi:10.1161/01.STR.0000157949.34986.30 15761206
52 Labovitz DL, Boden-Albala B, Hauser WA, Sacco RL. Lacunar infarct or deep intracerebral hemorrhage: who gets which? The Northern Manhattan Study. Neurology. 2007;68(8):606-608. doi:10.1212/01.wnl.0000254619.98089.43 17310033
53 Longstreth WT, Jr., Bernick C, Manolio TA, Bryan N, Jungreis CA, Price TR. Lacunar infarcts defined by magnetic resonance imaging of 3660 elderly people: the Cardiovascular Health Study. Arch Neurol. 1998;55(9):1217-1225. doi:10.1001/archneur.55.9.1217 9740116
54 Abu-Lebdeh HS, Hodge DO, Nguyen TT. Predictors of macrovascular disease in patients with type 2 diabetes mellitus. Mayo Clin Proc. 2001;76(7):707-712. doi:10.4065/76.7.707 11444403
55 Lehto S, Rönnemaa T, Pyörälä K, Laakso M. Predictors of stroke in middle-aged patients with non-insulin-dependent diabetes. Stroke. 1996;27(1):63-68. doi:10.1161/01.str.27.1.63 8553405
56 Hägg S, Thorn LM, Forsblom CM, et al. Different risk factor profiles for ischemic and hemorrhagic stroke in type 1 diabetes mellitus. Stroke. 2014;45(9):2558-2562. doi:10.1161/STROKEAHA.114.005724 25061078
57 Rawshani A, Rawshani A, Franzén S, et al. Risk factors, mortality, and cardiovascular outcomes in patients with type 2 diabetes. N Engl J Med. 2018;379(7):633-644. doi:10.1056/NEJMoa1800256 30110583
58 Rawshani A, Rawshani A, Sattar N, et al. Relative prognostic importance and optimal levels of risk factors for mortality and cardiovascular outcomes in type 1 diabetes mellitus. Circulation. 2019;139(16):1900-1912. doi:10.1161/CIRCULATIONAHA.118.037454 30798638
59 Hu G, Sarti C, Jousilahti P, et al. The impact of history of hypertension and type 2 diabetes at baseline on the incidence of stroke and stroke mortality. Stroke. 2005;36(12):2538-2543. doi:10.1161/01.STR.0000190894.30964.75 16282538
60 Sehestedt T, Hansen TW, Li Y, et al. Are blood pressure and diabetes additive or synergistic risk factors? Outcome in 8494 subjects randomly recruited from 10 populations. Hypertens Res. 2011;34(6):714-721. doi:10.1038/hr.2011.6 21307869
61 Zhang Y, Jiang X, Bo J, et al. Risk of stroke and coronary heart disease among various levels of blood pressure in diabetic and nondiabetic Chinese patients. J Hypertens. 2018;36(1):93-100. doi:10.1097/HJH.0000000000001528 29210861
62 Hedén Ståhl C, Lind M, Svensson A-M, et al. Long-term excess risk of stroke in people with type 2 diabetes in Sweden according to blood pressure level: a population-based case-control study. Diabet Med. 2017;34(4):522-530. doi:10.1111/dme.13292 27885698
63 Brouwer TF, Vehmeijer JT, Kalkman DN, et al. Intensive blood pressure lowering in patients with and patients without type 2 diabetes: a pooled analysis from two randomized trials. Diabetes Care. 2018;41(6):1142-1148. doi:10.2337/dc17-1722 29212825
64 Nazarzadeh M, Bidel Z, Canoy D, et al. Blood pressure-lowering treatment for prevention of major cardiovascular diseases in people with and without type 2 diabetes: an individual participant-level data meta-analysis. Lancet Diabetes Endocrinol. 2022;10(9):645-654. doi:10.1016/S2213-8587(22)00172-3 35878651
65 Suzuki Y, Kaneko H, Yano Y, et al. Interaction of blood pressure and glycemic status in developing cardiovascular disease: analysis of a nationwide real-world database. J Am Heart Assoc. 2023;12(1):e026192. doi:10.1161/JAHA.122.026192 36565182
66 Seidu S, Hambling CE, Kunutsor SK, Topsever P. Associations of blood pressure with cardiovascular and mortality outcomes in over 2 million older persons with or without diabetes mellitus: a systematic review and meta-analysis of 45 cohort studies. Prim Care Diabetes. 2023;17(6):554-567. doi:10.1016/j.pcd.2023.09.007 37806800
67 Tirschwell DL, Smith NL, Heckbert SR, Lemaitre RN, Longstreth WT, Jr., Psaty BM. Association of cholesterol with stroke risk varies in stroke subtypes and patient subgroups. Neurology. 2004;63(10):1868-1875. doi:10.1212/01.wnl.0000144282.42222.da 15557504
68 Lee JS, Chang PY, Zhang Y, Kizer JR, Best LG, Howard BV. Triglyceride and HDL-C dyslipidemia and risks of coronary heart disease and ischemic stroke by glycemic dysregulation status: the Strong Heart Study. Diabetes Care. 2017;40(4):529-537. doi:10.2337/dc16-1958 28122840
69 Wang N, Fulcher J, Abeysuriya N, et al. Intensive LDL cholesterol-lowering treatment beyond current recommendations for the prevention of major vascular events: a systematic review and meta-analysis of randomised trials including 327 037 participants. Lancet Diabetes Endocrinol. 2020;8(1):36-49. doi:10.1016/S2213-8587(19)30388-2 31862150
70 Wu Z, Huang Z, Lichtenstein AH, et al. Different associations between HDL cholesterol and cardiovascular diseases in people with diabetes mellitus and people without diabetes mellitus: a prospective community-based study. Am J Clin Nutr. 2021;114(3):907-913. doi:10.1093/ajcn/nqab163 34019626
71 Ishibashi T, Kaneko H, Matsuoka S, et al. HDL cholesterol and clinical outcomes in diabetes mellitus. Eur J Prev Cardiol. 2023;30(8):646-653. doi:10.1093/eurjpc/zwad029 36738171
72 Lou H, Dong Z, Zhang P, et al. Interaction of diabetes and smoking on stroke: a population-based cross-sectional survey in China. BMJ Open. 2018;8(4):e017706. doi:10.1136/bmjopen-2017-017706 29622573
73 Yang Y, Peng N, Chen G, et al. Interaction between smoking and diabetes in relation to subsequent risk of cardiovascular events. Cardiovasc Diabetol. 2022;21(1):14. doi:10.1186/s12933-022-01447-2 35073925
74 Boden-Albala B, Cammack S, Chong J, et al. Diabetes, fasting glucose levels, and risk of ischemic stroke and vascular events: findings from the Northern Manhattan Study (NOMAS). Diabetes Care. 2008;31(6):1132-1137. doi:10.2337/dc07-0797 18339972
75 Shi H, Ge Y, Wang H, Zhang Y, Teng W, Tian L. Fasting blood glucose and risk of stroke: a dose-response meta-analysis. Clin Nutr. 2021;40(5):3296-3304. doi:10.1016/j.clnu.2020.10.054 33189424
76 Bonora E, Tuomilehto J. The pros and cons of diagnosing diabetes with A1C. Diabetes Care. 2011;34 Suppl 2(Suppl 2):S184-S190. doi:10.2337/dc11-s216
77 Mitsios JP, Ekinci EI, Mitsios GP, Churilov L, Thijs V. Relationship between glycated hemoglobin and stroke risk: a systematic review and meta-analysis. J Am Heart Assoc. 2018;7(11):e007858. doi:10.1161/JAHA.117.007858 29773578
78 Iwase M, Komorita Y, Ohkuma T, et al. Incidence of stroke and its association with glycemic control and lifestyle in Japanese patients with type 2 diabetes mellitus: the Fukuoka diabetes registry. Diabetes Res Clin Pract. 2021;172:108518. doi:10.1016/j.diabres.2020.108518 33096191
79 Zabala A, Darsalia V, Holzmann MJ, et al. Risk of first stroke in people with type 2 diabetes and its relation to glycaemic control: a nationwide observational study. Diabetes Obes Metab. 2020;22(2):182-190. doi:10.1111/dom.13885 31576643
80 Saliba W, Barnett-Griness O, Gronich N, et al. Association of diabetes and glycated hemoglobin with the risk of intracerebral hemorrhage: a population-based cohort study. Diabetes Care. 2019;42(4):682-688. doi:10.2337/dc18-2472 30728223
81 Ståhl CH, Lind M, Svensson AM, Gudbjörnsdottir S, Mårtensson A, Rosengren A. Glycaemic control and excess risk of ischaemic and haemorrhagic stroke in patients with type 1 diabetes: a cohort study of 33 453 patients. J Intern Med. 2017;281(3):261-272. doi:10.1111/joim.12572 27925333
82 Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) Research Group. Risk factors for cardiovascular disease in type 1 diabetes. Diabetes. 2016;65(5):1370-1379. doi:10.2337/db15-1517 26895792
83 Bebu I, Schade D, Braffett B, et al. Risk factors for first and subsequent CVD events in type 1 diabetes: the DCCT/EDIC study. Diabetes Care. 2020;43(4):867-874. doi:10.2337/dc19-2292 32001614
84 Miller RG, Anderson SJ, Costacou T, Sekikawa A, Orchard TJ. Hemoglobin A1c level and cardiovascular disease incidence in persons with type 1 diabetes: an application of joint modeling of longitudinal and time-to-event data in the Pittsburgh Epidemiology of Diabetes Complications Study. Am J Epidemiol. 2018;187(7):1520-1529. doi:10.1093/aje/kwx386 29394305
85 Miller RG, Orchard TJ, Costacou T. 30-year cardiovascular disease in type 1 diabetes: risk and risk factors differ by long-term patterns of glycemic control. Diabetes Care. 2022;45(1):142-150. doi:10.2337/dc21-1381 34782353
86 Shen Y, Shi L, Nauman E, et al. Association between hemoglobin A1c and stroke risk in patients with type 2 diabetes. J Stroke. 2020;22(1):87-98. doi:10.5853/jos.2019.01704 32027794
87 Zhao W, Katzmarzyk PT, Horswell R, Wang Y, Johnson J, Hu G. Sex differences in the risk of stroke and HbA(1c) among diabetic patients. Diabetologia. 2014;57(5):918-926. doi:10.1007/s00125-014-3190-3 24577725
88 Lin CC, Yang CP, Li CI, et al. Visit-to-visit variability of fasting plasma glucose as predictor of ischemic stroke: competing risk analysis in a national cohort of Taiwan Diabetes Study. BMC Med. 2014;12:165. doi:10.1186/s12916-014-0165-7 25255837
89 Lee DY, Han K, Park S, et al. Glucose variability and the risks of stroke, myocardial infarction, and all-cause mortality in individuals with diabetes: retrospective cohort study. Cardiovasc Diabetol. 2020;19(1):144. doi:10.1186/s12933-020-01134-0 32962711
90 Scott ES, Januszewski AS, O’Connell R, et al. Long-term glycemic variability and vascular complications in type 2 diabetes: post hoc analysis of the FIELD study. J Clin Endocrinol Metab. 2020;105(10):dgaa361. doi:10.1210/clinem/dgaa361 32766757
91 Ren X, Wang Z, Guo C. Long-term glycemic variability and risk of stroke in patients with diabetes: a meta-analysis. Diabetol Metab Syndr. 2022;14(1):6. doi:10.1186/s13098-021-00770-0 35022087
92 Lee MY, Hsiao PJ, Huang YT, et al. Greater HbA1c variability is associated with increased cardiovascular events in type 2 diabetes patients with preserved renal function, but not in moderate to advanced chronic kidney disease. PLoS One. 2017;12(6):e0178319. doi:10.1371/journal.pone.0178319 28591149
93 Li S, Nemeth I, Donnelly L, Hapca S, Zhou K, Pearson ER. Visit-to-visit HbA(1c) variability is associated with cardiovascular disease and microvascular complications in patients with newly diagnosed type 2 diabetes. Diabetes Care. 2020;43(2):426-432. doi:10.2337/dc19-0823 31727686
94 Sato M, Inaishi J, Saisho Y, Sato Y, Komuro I, Itoh H. Association of visit-to-visit glycemic variability with risk of cardiovascular diseases in high-risk Japanese patients with type 2 diabetes: a subanalysis of the EMPATHY trial. J Diabetes Investig. 2021;12(12):2190-2196. doi:10.1111/jdi.13597 34013644
95 Shen Y, Zhou J, Shi L, et al. Association between visit-to-visit HbA1c variability and the risk of cardiovascular disease in patients with type 2 diabetes. Diabetes Obes Metab. 2021;23(1):125-135. doi:10.1111/dom.14201 32965068
96 Ceriello A, Lucisano G, Prattichizzo F, et al. HbA1c variability predicts cardiovascular complications in type 2 diabetes regardless of being at glycemic target. Cardiovasc Diabetol. 2022;21(1):13. doi:10.1186/s12933-022-01445-4 35073913
97 Horton WB, Snell-Bergeon JK. Hemoglobin A1c variability metrics predict coronary artery calcium and cardiovascular events in type 1 diabetes: the CACTI study. J Clin Endocrinol Metab. 2023;108(7):e444-e449. doi:10.1210/clinem/dgad019 36637994
98 Wadén J, Forsblom C, Thorn LM, et al. A1C variability predicts incident cardiovascular events, microalbuminuria, and overt diabetic nephropathy in patients with type 1 diabetes. Diabetes. 2009;58(11):2649-2655. doi:10.2337/db09-0693 19651819
99 Harjutsalo V, Barlovic DP, Gordin D, et al. Presence and determinants of cardiovascular disease and mortality in individuals with type 1 diabetes of long duration: the FinnDiane 50 Years of Diabetes Study. Diabetes Care. 2021;44(8):1885-1893. doi:10.2337/dc20-2816 34162664
100 Rotbain Curovic V, Theilade S, Winther SA, et al. Visit-to-visit variability of clinical risk markers in relation to long-term complications in type 1 diabetes. Diabet Med. 2021;38(5):e14459. doi:10.1111/dme.14459 33179275
101 Air EL, Kissela BM. Diabetes, the metabolic syndrome, and ischemic stroke: epidemiology and possible mechanisms. Diabetes Care. 2007;30(12):3131-3140. doi:10.2337/dc06-1537 17848611
102 Eckel RH, Grundy SM, Zimmet PZ. The metabolic syndrome. Lancet. 2005;365(9468):1415-1428. doi:10.1016/S0140-6736(05)66378-7 15836891
103 Mottillo S, Filion KB, Genest J, et al. The metabolic syndrome and cardiovascular risk a systematic review and meta-analysis. J Am Coll Cardiol. 2010;56(14):1113-1132. doi:10.1016/j.jacc.2010.05.034 20863953
104 DeBoer MD, Filipp SL, Sims M, Musani SK, Gurka MJ. Risk of ischemic stroke increases over the spectrum of metabolic syndrome severity. Stroke. 2020;51(8):2548-2552. doi:10.1161/STROKEAHA.120.028944 32552367
105 Najarian RM, Sullivan LM, Kannel WB, Wilson PW, D’Agostino RB, Wolf PA. Metabolic syndrome compared with type 2 diabetes mellitus as a risk factor for stroke: the Framingham Offspring Study. Arch Intern Med. 2006;166(1):106-111. doi:10.1001/archinte.166.1.106 16401818
106 Cull CA, Jensen CC, Retnakaran R, Holman RR. Impact of the metabolic syndrome on macrovascular and microvascular outcomes in type 2 diabetes mellitus: United Kingdom Prospective Diabetes Study 78. Circulation. 2007;116(19):2119-2126. doi:10.1161/CIRCULATIONAHA.107.733428 17967769
107 Protopsaltis I, Korantzopoulos P, Milionis HJ, et al. Metabolic syndrome and its components as predictors of ischemic stroke in type 2 diabetic patients. Stroke. 2008;39(3):1036-1038. doi:10.1161/STROKEAHA.107.498311 18239165
108 Chen XY, Thomas GN, Chen YK, Chan JC, Wong KS. Atherosclerotic vascular disease rather than metabolic syndrome predicts ischemic stroke in diabetic patients. Cerebrovasc Dis. 2010;30(4):374-379. doi:10.1159/000319570 20693792
109 Udell JA, Steg PG, Scirica BM, et al. Metabolic syndrome, diabetes mellitus, or both and cardiovascular risk in outpatients with or at risk for atherothrombosis. Eur J Prev Cardiol. 2014;21(12):1531-1540. doi:10.1177/2047487313500541 23918840
110 McGill M, Molyneaux L, Twigg SM, Yue DK. The metabolic syndrome in type 1 diabetes: does it exist and does it matter? J Diabetes Complications. 2008;22(1):18-23. doi:10.1016/j.jdiacomp.2006.10.005 18191073
111 Thorn LM, Forsblom C, Wadén J, et al. Metabolic syndrome as a risk factor for cardiovascular disease, mortality, and progression of diabetic nephropathy in type 1 diabetes. Diabetes Care. 2009;32(5):950-952. doi:10.2337/dc08-2022 19196885
112 Merger SR, Kerner W, Stadler M, et al. Prevalence and comorbidities of double diabetes. Diabetes Res Clin Pract. 2016;119:48-56. doi:10.1016/j.diabres.2016.06.003 27449710
113 Lee AS, Twigg SM, Flack JR. Metabolic syndrome in type 1 diabetes and its association with diabetes complications. Diabet Med. 2021;38(2):e14376. doi:10.1111/dme.14376 32738821
114 Kilpatrick ES, Rigby AS, Atkin SL. Insulin resistance, the metabolic syndrome, and complication risk in type 1 diabetes: “double diabetes” in the Diabetes Control and Complications Trial. Diabetes Care. 2007;30(3):707-712. doi:10.2337/dc06-1982 17327345
115 Pambianco G, Costacou T, Orchard TJ. The prediction of major outcomes of type 1 diabetes: a 12-year prospective evaluation of three separate definitions of the metabolic syndrome and their components and estimated glucose disposal rate: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes Care. 2007;30(5):1248-1254. doi:10.2337/dc06-2053 17303788
116 Bonora E, Targher G, Alberiche M, et al. Homeostasis model assessment closely mirrors the glucose clamp technique in the assessment of insulin sensitivity: studies in subjects with various degrees of glucose tolerance and insulin sensitivity. Diabetes Care. 2000;23(1):57-63. doi:10.2337/diacare.23.1.57 10857969
117 Wallace TM, Levy JC, Matthews DR. Use and abuse of HOMA modeling. Diabetes Care. 2004;27(6):1487-1495. doi:10.2337/diacare.27.6.1487 15161807
118 Wang T, Li M, Zeng T, et al. Association between insulin resistance and cardiovascular disease risk varies according to glucose tolerance status: a nationwide prospective cohort study. Diabetes Care. 2022;45(8):1863-1872. doi:10.2337/dc22-0202 35700159
119 Robins SJ, Rubins HB, Faas FH, et al. Insulin resistance and cardiovascular events with low HDL cholesterol: the Veterans Affairs HDL Intervention Trial (VA-HIT). Diabetes Care. 2003;26(5):1513-1517. doi:10.2337/diacare.26.5.1513 12716814
120 Bonora E, Kiechl S, Willeit J, et al. Insulin resistance as estimated by homeostasis model assessment predicts incident symptomatic cardiovascular disease in Caucasian subjects from the general population: the Bruneck study. Diabetes Care. 2007;30(2):318-324. doi:10.2337/dc06-0919 17259501
121 Bonora E, Formentini G, Calcaterra F, et al. HOMA-estimated insulin resistance is an independent predictor of cardiovascular disease in type 2 diabetic subjects: prospective data from the Verona Diabetes Complications Study. Diabetes Care. 2002;25(7):1135-1141. doi:10.2337/diacare.25.7.1135 12087010
122 Adler AI, Levy JC, Matthews DR, Stratton IM, Hines G, Holman RR. Insulin sensitivity at diagnosis of type 2 diabetes is not associated with subsequent cardiovascular disease (UKPDS 67). Diabet Med. 2005;22(3):306-311. doi:10.1111/j.1464-5491.2004.01418.x 15717879
123 Su WY, Chen SC, Huang YT, et al. Comparison of the effects of fasting glucose, hemoglobin A(1c), and triglyceride-glucose index on cardiovascular events in type 2 diabetes mellitus. Nutrients. 2019;11(11):2838. doi:10.3390/nu11112838 31752391
124 Zhao Q, Zhang TY, Cheng YJ, et al. Impacts of triglyceride-glucose index on prognosis of patients with type 2 diabetes mellitus and non-ST-segment elevation acute coronary syndrome: results from an observational cohort study in China. Cardiovasc Diabetol. 2020;19(1):108. doi:10.1186/s12933-020-01086-5 32641127
125 Wang L, Cong HL, Zhang JX, et al. Triglyceride-glucose index predicts adverse cardiovascular events in patients with diabetes and acute coronary syndrome. Cardiovasc Diabetol. 2020;19(1):80. doi:10.1186/s12933-020-01054-z 32534586
126 Zhang Y, Ding X, Hua B, et al. Predictive effect of triglyceride‑glucose index on clinical events in patients with type 2 diabetes mellitus and acute myocardial infarction: results from an observational cohort study in China. Cardiovasc Diabetol. 2021;20(1):43. doi:10.1186/s12933-021-01236-3 33573649
127 Ma X, Dong L, Shao Q, et al. Triglyceride glucose index for predicting cardiovascular outcomes after percutaneous coronary intervention in patients with type 2 diabetes mellitus and acute coronary syndrome. Cardiovasc Diabetol. 2020;19(1):31. doi:10.1186/s12933-020-01006-7 32156279
128 Hong S, Han K, Park CY. The triglyceride glucose index is a simple and low-cost marker associated with atherosclerotic cardiovascular disease: a population-based study. BMC Med. 2020;18(1):361. doi:10.1186/s12916-020-01824-2 33234146
129 Tai S, Fu L, Zhang N, Zhou Y, Xing Z, Wang Y. Impact of baseline and trajectory of triglyceride-glucose index on cardiovascular outcomes in patients with type 2 diabetes mellitus. Front Endocrinol (Lausanne). 2022;13:858209. doi:10.3389/fendo.2022.858209 35399955
130 Tai S, Fu L, Zhang N, et al. Association of the cumulative triglyceride-glucose index with major adverse cardiovascular events in patients with type 2 diabetes. Cardiovasc Diabetol. 2022;21(1):161. doi:10.1186/s12933-022-01599-1 35999546
131 Liu C, Liang D. The association between the triglyceride-glucose index and the risk of cardiovascular disease in US population aged ≤65 years with prediabetes or diabetes: a population-based study. Cardiovasc Diabetol. 2024;23(1):168. doi:10.1186/s12933-024-02261-8 38741118
132 Zabala A, Darsalia V, Lind M, et al. Estimated glucose disposal rate and risk of stroke and mortality in type 2 diabetes: a nationwide cohort study. Cardiovasc Diabetol. 2021;20(1):202. doi:10.1186/s12933-021-01394-4 34615525
133 Čypaitė G, Šimonienė D, Rudminaitė E. Relationship of insulin resistance with microvascular and macrovascular complications, death rate and other factors in patients with type 2 diabetes: a case-control study. Int J Clin Endocrinol Metab. 2024;10(1):006-013. doi:10.17352/ijcem.000060
134 Ren X, Jiang M, Han L, Zheng X. Estimated glucose disposal rate and risk of cardiovascular disease: evidence from the China Health and Retirement Longitudinal Study. BMC Geriatr. 2022;22(1):968. doi:10.1186/s12877-022-03689-x 36517754
135 Sun R, Wang J, Li M, et al. Association of insulin resistance with cardiovascular disease and all-cause mortality in type 1 diabetes: systematic review and meta-analysis. Diabetes Care. 2024;47(12):2266-2274. doi:10.2337/dc24-0475 39018337
136 Gerstein HC, Mann JF, Yi Q, et al. Albuminuria and risk of cardiovascular events, death, and heart failure in diabetic and nondiabetic individuals. JAMA. 2001;286(4):421-426. doi:10.1001/jama.286.4.421 11466120
137 Freedman BI, Langefeld CD, Lohman KK, et al. Relationship between albuminuria and cardiovascular disease in type 2 diabetes. J Am Soc Nephrol. 2005;16(7):2156-2161. doi:10.1681/ASN.2004100884 15872076
138 Bouchi R, Babazono T, Yoshida N, et al. Association of albuminuria and reduced estimated glomerular filtration rate with incident stroke and coronary artery disease in patients with type 2 diabetes. Hypertens Res. 2010;33(12):1298-1304. doi:10.1038/hr.2010.170 20882027
139 Kaze AD, Jaar BG, Fonarow GC, Echouffo-Tcheugui JB. Diabetic kidney disease and risk of incident stroke among adults with type 2 diabetes. BMC Med. 2022;20(1):127. doi:10.1186/s12916-022-02317-0 35346165
140 Ninomiya T, Perkovic V, de Galan BE, et al. Albuminuria and kidney function independently predict cardiovascular and renal outcomes in diabetes. J Am Soc Nephrol. 2009;20(8):1813-1821. doi:10.1681/ASN.2008121270 19443635
141 Drury PL, Ting R, Zannino D, et al. Estimated glomerular filtration rate and albuminuria are independent predictors of cardiovascular events and death in type 2 diabetes mellitus: the Fenofibrate Intervention and Event Lowering in Diabetes (FIELD) study. Diabetologia. 2011;54(1):32-43. doi:10.1007/s00125-010-1854-1 20668832
142 Fangel MV, Nielsen PB, Kristensen JK, et al. Albuminuria and risk of cardiovascular events and mortality in a general population of patients with type 2 diabetes without cardiovascular disease: a Danish cohort study. Am J Med. 2020;133(6):e269-e279. doi:10.1016/j.amjmed.2019.10.042 32205071
143 Hitman GA, Colhoun H, Newman C, et al. Stroke prediction and stroke prevention with atorvastatin in the Collaborative Atorvastatin Diabetes Study (CARDS). Diabet Med. 2007;24(12):1313-1321. doi:10.1111/j.1464-5491.2007.02268.x 17894827
144 Araki S, Haneda M, Koya D, et al. Reduction in microalbuminuria as an integrated indicator for renal and cardiovascular risk reduction in patients with type 2 diabetes. Diabetes. 2007;56(6):1727-1730. doi:10.2337/db06-1646 17360976
145 Jun M, Ohkuma T, Zoungas S, et al. Changes in albuminuria and the risk of major clinical outcomes in diabetes: results from ADVANCE-ON. Diabetes Care. 2018;41(1):163-170. doi:10.2337/dc17-1467 29079715
146 Waijer SW, Xie D, Inzucchi SE, et al. Short-term changes in albuminuria and risk of cardiovascular and renal outcomes in type 2 diabetes mellitus: a post hoc analysis of the EMPA-REG OUTCOME trial. J Am Heart Assoc. 2020;9(18):e016976. doi:10.1161/JAHA.120.016976 32893717
147 Persson F, Bain SC, Mosenzon O, et al. Changes in albuminuria predict cardiovascular and renal outcomes in type 2 diabetes: a post hoc analysis of the LEADER trial. Diabetes Care. 2021;44(4):1020-1026. doi:10.2337/dc20-1622 33504496
148 Gubitosi-Klug R, Gao X, Pop-Busui R, et al. Associations of microvascular complications with the risk of cardiovascular disease in type 1 diabetes. Diabetes Care. 2021;44(7):1499-1505. doi:10.2337/dc20-3104 33980605
149 de Boer IH, Gao X, Cleary PA, et al. Albuminuria changes and cardiovascular and renal outcomes in type 1 diabetes: the DCCT/EDIC Study. Clin J Am Soc Nephrol. 2016;11(11):1969-1977. doi:10.2215/CJN.02870316 27797889
150 Jansson FJ, Forsblom C, Harjutsalo V, et al. Regression of albuminuria and its association with incident cardiovascular outcomes and mortality in type 1 diabetes: the FinnDiane Study. Diabetologia. 2018;61(5):1203-1211. doi:10.1007/s00125-018-4564-8 29423580
151 Hu K, Jiang M, Zhou Q, et al. Association of diabetic retinopathy with stroke: a systematic review and meta-analysis. Front Neurol. 2021;12:626996. doi:10.3389/fneur.2021.626996 33796063
152 Drinkwater JJ, Davis TME, Hellbusch V, Turner AW, Bruce DG, Davis WA. Retinopathy predicts stroke but not myocardial infarction in type 2 diabetes: the Fremantle Diabetes Study Phase II. Cardiovasc Diabetol. 2020;19(1):43. doi:10.1186/s12933-020-01018-3 32234054
153 Liu YJ, Zhao JY, Han WW, et al. Microvascular burden and long-term risk of stroke and dementia in type 2 diabetes mellitus. J Affect Disord. 2024;354:68-74. doi:10.1016/j.jad.2024.03.053 38479499
154 Xie J, Ikram MK, Cotch MF, et al. Association of diabetic macular edema and proliferative diabetic retinopathy with cardiovascular disease: a systematic review and meta-analysis. JAMA Ophthalmol. 2017;135(6):586-593. doi:10.1001/jamaophthalmol.2017.0988 28472362
155 Eriksson MI, Hietala K, Summanen P, et al. Stroke incidence increases with diabetic retinopathy severity and macular edema in type 1 diabetes. Cardiovasc Diabetol. 2024;23(1):136. doi:10.1186/s12933-024-02235-w 38664827
156 Gaede P, Hildebrandt P, Hess G, Parving HH, Pedersen O. Plasma N-terminal pro-brain natriuretic peptide as a major risk marker for cardiovascular disease in patients with type 2 diabetes and microalbuminuria. Diabetologia. 2005;48(1):156-163. doi:10.1007/s00125-004-1607-0 15619076
157 Hillis GS, Welsh P, Chalmers J, et al. The relative and combined ability of high-sensitivity cardiac troponin T and N-terminal pro-B-type natriuretic peptide to predict cardiovascular events and death in patients with type 2 diabetes. Diabetes Care. 2014;37(1):295-303. doi:10.2337/dc13-1165 24089534
158 Scirica BM, Bhatt DL, Braunwald E, et al. Prognostic implications of biomarker assessments in patients with type 2 diabetes at high cardiovascular risk: a secondary analysis of a randomized clinical trial. JAMA Cardiol. 2016;1(9):989-998. doi:10.1001/jamacardio.2016.3030 27681000
159 Sharif S, Van der Graaf Y, Cramer MJ, et al. Low-grade inflammation as a risk factor for cardiovascular events and all-cause mortality in patients with type 2 diabetes. Cardiovasc Diabetol. 2021;20(1):220. doi:10.1186/s12933-021-01409-0 34753497
160 Gedebjerg A, Bjerre M, Kjaergaard AD, et al. CRP, C-peptide, and risk of first-time cardiovascular events and mortality in early type 2 diabetes: a Danish cohort study. Diabetes Care. 2023;46(5):1037-1045. doi:10.2337/dc22-1353 36930691
161 Coppola G, Corrado E, Muratori I, et al. Increased levels of C-reactive protein and fibrinogen influence the risk of vascular events in patients with NIDDM. Int J Cardiol. 2006;106(1):16-20. doi:10.1016/j.ijcard.2004.12.051 16321660
162 Herder C, Schöttker B, Rothenbacher D, et al. Interleukin-6 in the prediction of primary cardiovascular events in diabetes patients: results from the ESTHER study. Atherosclerosis. 2011;216(1):244-247. doi:10.1016/j.atherosclerosis.2011.01.041 21334625
163 Trøseid M, Seljeflot I, Hjerkinn EM, Arnesen H. Interleukin-18 is a strong predictor of cardiovascular events in elderly men with the metabolic syndrome: synergistic effect of inflammation and hyperglycemia. Diabetes Care. 2009;32(3):486-492. doi:10.2337/dc08-1710 19092166
164 Gellen B, Thorin-Trescases N, Sosner P, et al. ANGPTL2 is associated with an increased risk of cardiovascular events and death in diabetic patients. Diabetologia. 2016;59(11):2321-2330. doi:10.1007/s00125-016-4066-5 27491833
165 Gellen B, Thorin-Trescases N, Thorin E, et al. Serum tenascin-C is independently associated with increased major adverse cardiovascular events and death in individuals with type 2 diabetes: a French prospective cohort. Diabetologia. 2020;63(5):915-923. doi:10.1007/s00125-020-05108-5 32040670
166 Colhoun HM, Betteridge DJ, Durrington P, et al. Total soluble and endogenous secretory receptor for advanced glycation end products as predictive biomarkers of coronary heart disease risk in patients with type 2 diabetes: an analysis from the CARDS trial. Diabetes. 2011;60(9):2379-2385. doi:10.2337/db11-0291 21771973
167 Thomas MC, Woodward M, Neal B, et al. Relationship between levels of advanced glycation end products and their soluble receptor and adverse outcomes in adults with type 2 diabetes. Diabetes Care. 2015;38(10):1891-1897. doi:10.2337/dc15-0925 26253728
168 Koska J, Saremi A, Howell S, et al. Advanced glycation end products, oxidation products, and incident cardiovascular events in patients with type 2 diabetes. Diabetes Care. 2018;41(3):570-576. doi:10.2337/dc17-1740 29208654
169 Fujisawa K, Katakami N, Kaneto H, et al. Circulating soluble RAGE as a predictive biomarker of cardiovascular event risk in patients with type 2 diabetes. Atherosclerosis. 2013;227(2):425-428. doi:10.1016/j.atherosclerosis.2013.01.016 23384720
170 Hanssen NM, Beulens JW, van Dieren S, et al. Plasma advanced glycation end products are associated with incident cardiovascular events in individuals with type 2 diabetes: a case-cohort study with a median follow-up of 10 years (EPIC-NL). Diabetes. 2015;64(1):257-265. doi:10.2337/db13-1864 24848072
171 Sabbatinelli J, Castiglione S, Macrì F, et al. Circulating levels of AGEs and soluble RAGE isoforms are associated with all-cause mortality and development of cardiovascular complications in type 2 diabetes: a retrospective cohort study. Cardiovasc Diabetol. 2022;21(1):95. doi:10.1186/s12933-022-01535-3 35668468
172 Nakamura T, Tsujimoto T, Yasuda K, Ueki K, Kajio H. Continuous low serum levels of advanced glycation end products and low risk of cardiovascular disease in patients with poorly controlled type 2 diabetes. Cardiovasc Diabetol. 2023;22(1):147. doi:10.1186/s12933-023-01882-9 37353776
173 Gerstein HC, Paré G, McQueen MJ, et al. Identifying novel biomarkers for cardiovascular events or death in people with dysglycemia. Circulation. 2015;132(24):2297-2304. doi:10.1161/CIRCULATIONAHA.115.015744 26518765
174 Looker HC, Colombo M, Agakov F, et al. Protein biomarkers for the prediction of cardiovascular disease in type 2 diabetes. Diabetologia. 2015;58(6):1363-1371. doi:10.1007/s00125-015-3535-6 25740695
175 van der Leeuw J, Beulens JW, van Dieren S, et al. Novel biomarkers to improve the prediction of cardiovascular event risk in type 2 diabetes mellitus. J Am Heart Assoc. 2016;5(6):e003048. doi:10.1161/JAHA.115.003048 27247335
176 Nowak C, Carlsson AC, Östgren CJ, et al. Multiplex proteomics for prediction of major cardiovascular events in type 2 diabetes. Diabetologia. 2018;61(8):1748-1757. doi:10.1007/s00125-018-4641-z 29796748
177 Bachmann KN, Wang TJ. Biomarkers of cardiovascular disease: contributions to risk prediction in individuals with diabetes. Diabetologia. 2018;61(5):987-995. doi:10.1007/s00125-017-4442-9 28956084
178 Miller RG, Costacou T, Orchard TJ. Lipoprotein-associated phospholipase A2, C-reactive protein, and coronary artery disease in individuals with type 1 diabetes and macroalbuminuria. Diab Vasc Dis Res. 2010;7(1):47-55. doi:10.1177/1479164109346358 20368232
179 Schram MT, Chaturvedi N, Schalkwijk CG, Fuller JH, Stehouwer CD, EURODIAB Prospective Complications Study Group. Markers of inflammation are cross-sectionally associated with microvascular complications and cardiovascular disease in type 1 diabetes—the EURODIAB Prospective Complications Study. Diabetologia. 2005;48(2):370-378. doi:10.1007/s00125-004-1628-8 15692810
180 Costacou T, Zgibor JC, Evans RW, et al. The prospective association between adiponectin and coronary artery disease among individuals with type 1 diabetes. The Pittsburgh Epidemiology of Diabetes Complications Study. Diabetologia. 2005;48(1):41-48. doi:10.1007/s00125-004-1597-y 15616802
181 Nin JW, Jorsal A, Ferreira I, et al. Higher plasma levels of advanced glycation end products are associated with incident cardiovascular disease and all-cause mortality in type 1 diabetes: a 12-year follow-up study. Diabetes Care. 2011;34(2):442-447. doi:10.2337/dc10-1087 21270199
182 Adeshara K, Gordin D, Antikainen AA, et al. Protein glycation products associate with progression of kidney disease and incident cardiovascular events in individuals with type 1 diabetes. Cardiovasc Diabetol. 2024;23(1):235. doi:10.1186/s12933-024-02316-w 38965604
183 Hunt KJ, Baker NL, Cleary PA, et al. Longitudinal association between endothelial dysfunction, inflammation, and clotting biomarkers with subclinical atherosclerosis in type 1 diabetes: an evaluation of the DCCT/EDIC cohort. Diabetes Care. 2015;38(7):1281-1289. doi:10.2337/dc14-2877 25852210
184 Strausz S, Havulinna AS, Tuomi T, et al. Obstructive sleep apnoea and the risk for coronary heart disease and type 2 diabetes: a longitudinal population-based study in Finland. BMJ Open. 2018;8(10):e022752. doi:10.1136/bmjopen-2018-022752 30327404
185 Labarca G, Dreyse J, Salas C, et al. Risk of mortality among patients with moderate to severe obstructive sleep apnea and diabetes mellitus: results from the SantOSA cohort. Sleep Breath. 2021;25(3):1467-1475. doi:10.1007/s11325-020-02283-y 33394326
186 Koo CY, Drager LF, Sethi R, et al. Obstructive sleep apnea and diabetes independently add to cardiovascular risk after coronary revascularization. Diabetes Care. 2018;41(2):e12-e14. doi:10.2337/dc17-0759 29208655
187 Wang X, Fan J, Du Y, et al. Clinical significance of obstructive sleep apnea in patients with acute coronary syndrome in relation to diabetes status. BMJ Open Diabetes Res Care. 2019;7(1):e000737. doi:10.1136/bmjdrc-2019-000737 31908793
188 Rice TB, Foster GD, Sanders MH, et al. The relationship between obstructive sleep apnea and self-reported stroke or coronary heart disease in overweight and obese adults with type 2 diabetes mellitus. Sleep. 2012;35(9):1293-1298. doi:10.5665/sleep.2090 22942508
189 Seicean S, Strohl KP, Seicean A, Gibby C, Marwick TH. Sleep disordered breathing as a risk of cardiac events in subjects with diabetes mellitus and normal exercise echocardiographic findings. Am J Cardiol. 2013;111(8):1214-1220. doi:10.1016/j.amjcard.2012.12.053 23415514
190 Adderley NJ, Subramanian A, Toulis K, et al. Obstructive sleep apnea, a risk factor for cardiovascular and microvascular disease in patients with type 2 diabetes: findings from a population-based cohort study. Diabetes Care. 2020;43(8):1868-1877. doi:10.2337/dc19-2116 32345651
191 Stadler S, Jalili S, Schreib A, et al. Association of sleep-disordered breathing with severe chronic vascular disease in patients with type 2 diabetes. Sleep Med. 2018;48:53-60. doi:10.1016/j.sleep.2018.05.001 29859478
192 Aung AT, Koo CY, Tam WW, et al. Sleep apnea and diabetes mellitus are independently associated with cardiovascular events and hospitalization for heart failure after coronary artery bypass grafting. Sci Rep. 2020;10(1):21664. doi:10.1038/s41598-020-78700-9 33303900
193 Manin G, Pons A, Baltzinger P, et al. Obstructive sleep apnoea in people with type 1 diabetes: prevalence and association with micro- and macrovascular complications. Diabet Med. 2015;32(1):90-96. doi:10.1111/dme.12582 25186832
194 Pépin JL, Bailly S, Texereau JB, et al. Prevalence of sleep apnoea in patients with type 1 diabetes and its association with comorbidities and diabetic complications: a French nationwide prospective study. Diabetes Obes Metab. 2023;25(6):1624-1631. doi:10.1111/dom.15015 36792920
195 Kuehl M, Stevens MJ. Cardiovascular autonomic neuropathies as complications of diabetes mellitus. Nat Rev Endocrinol. 2012;8(7):405-416. doi:10.1038/nrendo.2012.21 22371159
196 Ko SH, Song KH, Park SA, et al. Cardiovascular autonomic dysfunction predicts acute ischaemic stroke in patients with type 2 diabetes mellitus: a 7-year follow-up study. Diabet Med. 2008;25(10):1171-1177. doi:10.1111/j.1464-5491.2008.02567.x 19046195
197 Kaze AD, Yuyun MF, Fonarow GC, Echouffo-Tcheugui JB. Cardiac autonomic dysfunction and risk of incident stroke among adults with type 2 diabetes. Eur Stroke J. 2023;8(1):275-282. doi:10.1177/23969873221127108 37021204
198 Astrup AS, Tarnow L, Rossing P, Hansen BV, Hilsted J, Parving HH. Cardiac autonomic neuropathy predicts cardiovascular morbidity and mortality in type 1 diabetic patients with diabetic nephropathy. Diabetes Care. 2006;29(2):334-339. doi:10.2337/diacare.29.02.06.dc05-1242 16443883
199 Pop-Busui R, Braffett BH, Zinman B, et al. Cardiovascular autonomic neuropathy and cardiovascular outcomes in the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) study. Diabetes Care. 2017;40(1):94-100. doi:10.2337/dc16-1397 27803120
200 Cha SA, Yun JS, Lim TS, et al. Diabetic cardiovascular autonomic neuropathy predicts recurrent cardiovascular diseases in patients with type 2 diabetes. PLoS One. 2016;11(10):e0164807. doi:10.1371/journal.pone.0164807 27741306
201 Yun JS, Park YM, Cha SA, Ahn YB, Ko SH. Progression of cardiovascular autonomic neuropathy and cardiovascular disease in type 2 diabetes. Cardiovasc Diabetol. 2018;17(1):109. doi:10.1186/s12933-018-0752-6 30071872
202 Lai YR, Huang CC, Chang HW, et al. Severity of cardiovascular autonomic neuropathy is a predictor associated with major adverse cardiovascular events in adults with type 2 diabetes mellitus: a 6-year follow-up study. Can J Diabetes. 2021;45(2):155-161. doi:10.1016/j.jcjd.2020.06.017 33046397
203 Gerstein HC, Pogue J, Mann JF, et al. The relationship between dysglycaemia and cardiovascular and renal risk in diabetic and non-diabetic participants in the HOPE study: a prospective epidemiological analysis. Diabetologia. 2005;48(9):1749-1755. doi:10.1007/s00125-005-1858-4 16059716
204 Selvin E, Marinopoulos S, Berkenblit G, et al. Meta-analysis: glycosylated hemoglobin and cardiovascular disease in diabetes mellitus. Ann Intern Med. 2004;141(6):421-431. doi:10.7326/0003-4819-141-6-200409210-00007 15381515
205 Low Wang CC, Hess CN, Hiatt WR, Goldfine AB. Clinical update: cardiovascular disease in diabetes mellitus: atherosclerotic cardiovascular disease and heart failure in type 2 diabetes mellitus - mechanisms, management, and clinical considerations. Circulation. 2016;133(24):2459-2502. doi:10.1161/CIRCULATIONAHA.116.022194 27297342
206 UK Prospective Diabetes Study (UKPDS) Group. Intensive blood-glucose control with sulphonylureas or insulin compared with conventional treatment and risk of complications in patients with type 2 diabetes (UKPDS 33). Lancet. 1998;352(9131):837-853. doi:10.1016/S0140-6736(98)07019-6 9742976
207 UK Prospective Diabetes Study (UKPDS) Group. Effect of intensive blood-glucose control with metformin on complications in overweight patients with type 2 diabetes (UKPDS 34). Lancet. 1998;352(9131):854-865. doi:10.1016/S0140-6736(98)07037-8 9742977
208 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA. 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med. 2008;359(15):1577-1589. doi:10.1056/NEJMoa0806470 18784090
209 Action to Control Cardiovascular Risk in Diabetes Study Group, Gerstein HC, Miller ME, et al. Effects of intensive glucose lowering in type 2 diabetes. N Engl J Med. 2008;358(24):2545-2559. doi:10.1056/NEJMoa0802743 18539917
210 ADVANCE Collaborative Group, Patel A, MacMahon S, et al. Intensive blood glucose control and vascular outcomes in patients with type 2 diabetes. N Engl J Med. 2008;358(24):2560-2572. doi:10.1056/NEJMoa0802987 18539916
211 Duckworth W, Abraira C, Moritz T, et al. Glucose control and vascular complications in veterans with type 2 diabetes. N Engl J Med. 2009;360(2):129-139. doi:10.1056/NEJMoa0808431 19092145
212 The Diabetes Control and Complications Trial (DCCT) Research Group. Effect of intensive diabetes management on macrovascular events and risk factors in the Diabetes Control and Complications Trial. Am J Cardiol. 1995;75(14):894-903. doi:10.1016/s0002-9149(99)80683-3 7732997
213 Nathan DM, Cleary PA, Backlund JY, et al. Intensive diabetes treatment and cardiovascular disease in patients with type 1 diabetes. N Engl J Med. 2005;353(25):2643-2653. doi:10.1056/NEJMoa052187 16371630
214 Dormandy JA, Charbonnel B, Eckland DJ, et al. Secondary prevention of macrovascular events in patients with type 2 diabetes in the PROactive Study (PROspective pioglitAzone Clinical Trial In macroVascular Events): a randomised controlled trial. Lancet. 2005;366(9493):1279-1289. doi:10.1016/S0140-6736(05)67528-9 16214598
215 Wilcox R, Bousser MG, Betteridge DJ, et al. Effects of pioglitazone in patients with type 2 diabetes with or without previous stroke: results from PROactive (PROspective pioglitAzone Clinical Trial In macroVascular Events 04). Stroke. 2007;38(3):865-873. doi:10.1161/01.STR.0000257974.06317.49 17290029
216 Kernan WN, Viscoli CM, Furie KL, et al. Pioglitazone after ischemic stroke or transient ischemic attack. N Engl J Med. 2016;374(14):1321-1331. doi:10.1056/NEJMoa1506930 26886418
217 Zinman B, Wanner C, Lachin JM, et al. Empagliflozin, cardiovascular outcomes, and mortality in type 2 diabetes. N Engl J Med. 2015;373(22):2117-2128. doi:10.1056/NEJMoa1504720 26378978
218 Neal B, Perkovic V, Mahaffey KW, et al. Canagliflozin and cardiovascular and renal events in type 2 diabetes. N Engl J Med. 2017;377(7):644-657. doi:10.1056/NEJMoa1611925 28605608
219 Marso SP, Daniels GH, Brown-Frandsen K, et al. Liraglutide and cardiovascular outcomes in type 2 diabetes. N Engl J Med. 2016;375(4):311-322. doi:10.1056/NEJMoa1603827 27295427
220 Marso SP, Bain SC, Consoli A, et al. Semaglutide and cardiovascular outcomes in patients with type 2 diabetes. N Engl J Med. 2016;375(19):1834-1844. doi:10.1056/NEJMoa1607141 27633186
221 Gerstein HC, Colhoun HM, Dagenais GR, et al. Dulaglutide and cardiovascular outcomes in type 2 diabetes (REWIND): a double-blind, randomised placebo-controlled trial. Lancet. 2019;394(10193):121-130. doi:10.1016/S0140-6736(19)31149-3 31189511
222 American Diabetes Association Professional Practice Committee. 10. Cardiovascular Disease and Risk Management: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S207-S238. doi:10.2337/dc25-S010 39651970
223 Kleindorfer DO, Towfighi A, Chaturvedi S, et al. 2021 Guideline for the Prevention of Stroke in Patients With Stroke and Transient Ischemic Attack: a guideline from the American Heart Association/American Stroke Association. Stroke. 2021;52(7):e364-e467. doi:10.1161/STR.0000000000000375 34024117
224 Hankey GJ. Secondary stroke prevention. Lancet Neurol. 2014;13(2):178-194. doi:10.1016/S1474-4422(13)70255-2 24361114
225 Unger T, Borghi C, Charchar F, et al. 2020 International Society of Hypertension Global Hypertension Practice Guidelines. Hypertension. 2020;75(6):1334-1357. doi:10.1161/HYPERTENSIONAHA.120.15026 32370572
226 Whelton PK, Carey RM. The 2017 American College of Cardiology/American Heart Association Clinical Practice Guideline for High Blood Pressure in Adults. JAMA Cardiol. 2018;3(4):352-353. doi:10.1001/jamacardio.2018.0005 29466540
227 Whelton PK, Williams B. The 2018 European Society of Cardiology/European Society of Hypertension and 2017 American College of Cardiology/American Heart Association blood pressure guidelines: more similar than different. JAMA. 2018;320(17):1749-1750. doi:10.1001/jama.2018.16755 30398611
228 Curb JD, Pressel SL, Cutler JA, et al. Effect of diuretic-based antihypertensive treatment on cardiovascular disease risk in older diabetic patients with isolated systolic hypertension. Systolic Hypertension in the Elderly Program Cooperative Research Group. JAMA. 1996;276(23):1886-1892. doi:10.1001/jama.1996.03540230036032 8968014
229 Adler AI, Stratton IM, Neil HA, et al. Association of systolic blood pressure with macrovascular and microvascular complications of type 2 diabetes (UKPDS 36): prospective observational study. BMJ. 2000;321(7258):412-419. doi:10.1136/bmj.321.7258.412 10938049
230 Heart Outcomes Prevention Evaluation (HOPE) Study Investigators. Effects of ramipril on cardiovascular and microvascular outcomes in people with diabetes mellitus: results of the HOPE study and MICRO-HOPE substudy. Heart Outcomes Prevention Evaluation Study Investigators. Lancet. 2000;355(9200):253-259. doi:10.1016/S0140-6736(99)12323-7 10675071
231 Dahlöf B, Devereux RB, Kjeldsen SE, et al. Cardiovascular morbidity and mortality in the Losartan Intervention For Endpoint reduction in hypertension study (LIFE): a randomised trial against atenolol. Lancet. 2002;359(9311):995-1003. doi:10.1016/S0140-6736(02)08089-3 11937178
232 Patel A, ADVANCE Collaborative Group, MacMahon S, et al. Effects of a fixed combination of perindopril and indapamide on macrovascular and microvascular outcomes in patients with type 2 diabetes mellitus (the ADVANCE trial): a randomised controlled trial. Lancet. 2007;370(9590):829-840. doi:10.1016/S0140-6736(07)61303-8 17765963
233 Amarenco P, Goldstein LB, Szarek M, et al. Effects of intense low-density lipoprotein cholesterol reduction in patients with stroke or transient ischemic attack: the Stroke Prevention by Aggressive Reduction in Cholesterol Levels (SPARCL) trial. Stroke. 2007;38(12):3198-3204. doi:10.1161/STROKEAHA.107.493106 17962589
234 Gorelick PB, Whelton PK, Sorond F, Carey RM. Blood pressure management in stroke. Hypertension. 2020;76(6):1688-1695. doi:10.1161/HYPERTENSIONAHA.120.14653 33040620
235 UK Prospective Diabetes Study Group. Tight blood pressure control and risk of macrovascular and microvascular complications in type 2 diabetes: UKPDS 38. UK Prospective Diabetes Study Group. BMJ. 1998;317(7160):703-713. doi:10.1136/bmj.317.7160.703 9732337
236 Holman RR, Paul SK, Bethel MA, Neil HA, Matthews DR. Long-term follow-up after tight control of blood pressure in type 2 diabetes. N Engl J Med. 2008;359(15):1565-1576. doi:10.1056/NEJMoa0806359 18784091
237 Reboldi G, Gentile G, Angeli F, Ambrosio G, Mancia G, Verdecchia P. Effects of intensive blood pressure reduction on myocardial infarction and stroke in diabetes: a meta-analysis in 73,913 patients. J Hypertens. 2011;29(7):1253-1269. doi:10.1097/HJH.0b013e3283469976 21505352
238 Ioannidou E, Shabnam S, Abner S, et al. Effect of more versus less intensive blood pressure control on cardiovascular, renal and mortality outcomes in people with type 2 diabetes: a systematic review and meta-analysis. Diabetes Metab Syndr. 2023;17(6):102782. doi:10.1016/j.dsx.2023.102782 37257222
239 Yang Q, Zheng R, Wang S, et al. Systolic blood pressure control targets to prevent major cardiovascular events and death in patients with type 2 diabetes: a systematic review and network meta-analysis. Hypertension. 2023;80(8):1640-1653. doi:10.1161/HYPERTENSIONAHA.123.20954 37254768
240 ACCORD Study Group, Cushman WC, Evans GW, et al. Effects of intensive blood-pressure control in type 2 diabetes mellitus. N Engl J Med. 2010;362(17):1575-1585. doi:10.1056/NEJMoa1001286 20228401
241 Bi Y, Li M, Liu Y, et al. Intensive blood-pressure control in patients with type 2 diabetes. N Engl J Med. 2025;392(12):1155-1167. doi:10.1056/NEJMoa2412006 39555827
242 Nikkilä EA, Hormila P. Serum lipids and lipoproteins in insulin-treated diabetes. Demonstration of increased high density lipoprotein concentrations. Diabetes. 1978;27(11):1078-1086. doi:10.2337/diab.27.11.1078 214367
243 Schwab KO, Doerfer J, Marg W, Schober E, Holl RW, DPV Science Initiative and the Competence Network Diabetes Mellitus. Characterization of 33 488 children and adolescents with type 1 diabetes based on the gender-specific increase of cardiovascular risk factors. Pediatr Diabetes. 2010;11(5):357-363. doi:10.1111/j.1399-5448.2010.00665.x 20624248
244 Selvaraj M, Prasad HK, White S, Prasanna B, Sangaralingam T. Prevalence and determinants of occurrence of dyslipidemia in subjects with type 1 diabetes mellitus. Indian J Pediatr. 2023;90(2):118-123. doi:10.1007/s12098-022-04130-2 35366198
245 Clarke PM, Gray AM, Briggs A, et al. A model to estimate the lifetime health outcomes of patients with type 2 diabetes: the United Kingdom Prospective Diabetes Study (UKPDS) Outcomes Model (UKPDS no. 68). Diabetologia. 2004;47(10):1747-1759. doi:10.1007/s00125-004-1527-z 15517152
246 Colhoun HM, Betteridge DJ, Durrington PN, et al. Primary prevention of cardiovascular disease with atorvastatin in type 2 diabetes in the Collaborative Atorvastatin Diabetes Study (CARDS): multicentre randomised placebo-controlled trial. Lancet. 2004;364(9435):685-696. doi:10.1016/S0140-6736(04)16895-5 15325833
247 Cholesterol Treatment Trialists’ (CTT) Collaborators, Kearney PM, Blackwell L, et al. Efficacy of cholesterol-lowering therapy in 18,686 people with diabetes in 14 randomised trials of statins: a meta-analysis. Lancet. 2008;371(9607):117-125. doi:10.1016/S0140-6736(08)60104-X 18191683
248 Yang XH, Zhang BL, Cheng Y, Fu SK, Jin HM. Statin use and the risk of CVD events, stroke, and all-cause mortality in patients with diabetes: a systematic review and meta-analysis. Nutr Metab Cardiovasc Dis. 2022;32(11):2470-2482. doi:10.1016/j.numecd.2022.07.018 36064686
249 Zheng SL, Roddick AJ. Association of aspirin use for primary prevention with cardiovascular events and bleeding events: a systematic review and meta-analysis. JAMA. 2019;321(3):277-287. doi:10.1001/jama.2018.20578 30667501
250 Bowman L, Mafham M, Stevens W, et al. ASCEND: A Study of Cardiovascular Events iN Diabetes: characteristics of a randomized trial of aspirin and of omega-3 fatty acid supplementation in 15,480 people with diabetes. Am Heart J. 2018;198:135-144. doi:10.1016/j.ahj.2017.12.006 29653635
251 Ogawa H, Nakayama M, Morimoto T, et al. Low-dose aspirin for primary prevention of atherosclerotic events in patients with type 2 diabetes: a randomized controlled trial. JAMA. 2008;300(18):2134-2141. doi:10.1001/jama.2008.623 18997198
252 Bushnell C, Kernan WN, Sharrief AZ, et al. 2024 Guideline for the Primary Prevention of Stroke: a guideline from the American Heart Association/American Stroke Association. Stroke. 2024;55(12):e344-e424. doi:10.1161/STR.0000000000000475 39429201
253 De Schryver EL, Algra A, Kappelle LJ, van Gijn J, Koudstaal PJ. Vitamin K antagonists versus antiplatelet therapy after transient ischaemic attack or minor ischaemic stroke of presumed arterial origin. Cochrane Database Syst Rev. 2012;2012(9):CD001342. doi:10.1002/14651858.CD001342.pub3 22972051
254 Mohr JP, Thompson JL, Lazar RM, et al. A comparison of warfarin and aspirin for the prevention of recurrent ischemic stroke. N Engl J Med. 2001;345(20):1444-1451. doi:10.1056/NEJMoa011258 11794192
255 Walker MD, Marler JR, Goldstein M, et al. Endarterectomy for asymptomatic carotid artery stenosis. Executive Committee for the Asymptomatic Carotid Atherosclerosis Study. JAMA. 1995;273(18):1421-1428. doi:10.1001/jama.1995.03520420037035 7723155
256 Turan TN, Voeks JH, Chimowitz MI, et al. Rationale, design, and implementation of intensive risk factor treatment in the CREST2 trial. Stroke. 2020;51(10):2960-2971. doi:10.1161/STROKEAHA.120.030730 32951538
257 Powers WJ, Rabinstein AA, Ackerson T, et al. Guidelines for the Early Management of Patients With Acute Ischemic Stroke: 2019 Update to the 2018 Guidelines for the Early Management of Acute Ischemic Stroke: a guideline for healthcare professionals from the American Heart Association/American Stroke Association. Stroke. 2019;50(12):e344-e418. doi:10.1161/STR.0000000000000211 31662037
258 Southerland AM, Mayer SA, Chiota-McCollum NA, et al. Glucose control and risk of symptomatic intracerebral hemorrhage following thrombolysis for acute ischemic stroke: a SHINE trial analysis. Neurology. 2024;102(9):e209323. doi:10.1212/WNL.0000000000209323 38626363
259 Wu S, Mao Y, Chen S, et al. Safety and efficacy of tight versus loose glycemic control in acute stroke patients: a meta-analysis of randomized controlled trials. Int J Stroke. 2024;19(7):727-734. doi:10.1177/17474930241241994 38472157
260 Broocks G, Kemmling A, Aberle J, et al. Elevated blood glucose is associated with aggravated brain edema in acute stroke. J Neurol. 2020;267(2):440-448. doi:10.1007/s00415-019-09601-9 31667625
261 Johnston KC, Bruno A, Pauls Q, et al. Intensive vs standard treatment of hyperglycemia and functional outcome in patients with acute ischemic stroke: the SHINE randomized clinical trial. JAMA. 2019;322(4):326-335. doi:10.1001/jama.2019.9346 31334795
262 Chamorro Á, Brown S, Amaro S, et al. Glucose modifies the effect of endovascular thrombectomy in patients with acute stroke. Stroke. 2019;50(3):690-696. doi:10.1161/STROKEAHA.118.023769 30777000
263 Lau LH, Lew J, Borschmann K, Thijs V, Ekinci EI. Prevalence of diabetes and its effects on stroke outcomes: a meta-analysis and literature review. J Diabetes Investig. 2019;10(3):780-792. doi:10.1111/jdi.12932 30220102
264 Echouffo-Tcheugui JB, Xu H, Matsouaka RA, et al. Diabetes and long-term outcomes of ischaemic stroke: findings from Get With The Guidelines-Stroke. Eur Heart J. 2018;39(25):2376-2386. doi:10.1093/eurheartj/ehy036 29438515
265 Wang Y, Jiang G, Zhang J, Wang J, You W, Zhu J. Blood glucose level affects prognosis of patients who received intravenous thrombolysis after acute ischemic stroke? A meta-analysis. Front Endocrinol (Lausanne). 2023;14:1120779. doi:10.3389/fendo.2023.1120779 37124754

FIGURE 1.

Annual Adjusted Incidence of First-Ever Stroke, by Race and Stroke Type, Greater Cincinnati/Northern Kentucky Stroke Study, 1993–1994, 1999, 2005, 2010, 2015.

Data represent hospital and out-of-hospital ascertainment. Incidence rates are age-adjusted, race-adjusted, and sex-adjusted or age-adjusted and sex-adjusted to the 2010 U.S. population. ICH, intracerebral hemorrhage; SAH, subarachnoid hemorrhage.

SOURCE: Reference (35)

Bar graph showing that the incidence of ischemic stroke has decreased between 1993 and 2015 for white and black persons but has remained stable for intracerebral and subarchnoid hemorrhage.

FIGURE 2.

Annual Adjusted Incidence of First-Ever Stroke, by Sex and Stroke Type, Greater Cincinnati/Northern Kentucky Stroke Study, 1993–1994, 1999, 2005, 2010, 2015.

Data represent hospital and out-of-hospital ascertainment. Incidence rates are adjusted by age and race using standardization to the 2010 U.S. population. ICH, intracerebral hemorrhage; SAH, subarachnoid hemorrhage.

SOURCE: Reference (36)

Bar graph showing that the incidence of ischemic stroke has decreased between 1993 and 2015 for men and women but has remained stable for intracerebral and subarchnoid hemorrhage.

FIGURE 3.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status and Age, U.S., 2022–2023.

All data are self-reported. Diabetes is defined as self-report of a physician diagnosis. Error bars represent 95% confidence intervals.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that the prevalence of stroke increases with age and is greater for adults with diagnosed diabetes compared to those without diabetes.

FIGURE 4.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, and Sex, U.S., 2022–2023.

All data are self-reported. Diabetes is defined as self-report of a physician diagnosis. Error bars represent 95% confidence intervals.

^1^ Relative standard error >30%–40%

^2^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that prevalence of stroke increases with age and is greater for adults with diagnosed diabetes compared to those without diagnosed diabetes, regardless of sex.

FIGURE 5.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, and Race/Ethnicity, U.S., 2022–2023.

All data are self-reported. Diabetes is defined as self-report of a physician diagnosis. Error bars represent 95% confidence intervals.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that the prevalence of stroke was higher for adults with diabetes compared to those without diabetes, regardless of race or ethnicity and age.

FIGURE 6.

Age-Standardized Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status and State or Territory, U.S., 2022–2023.

All data are self-reported. Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional.

SOURCE: Behavioral Risk Factor Surveillance System 2022–2023

Graphic of the United States showing that stroke prevalence by state is higher for adults with diabetes compared to those without diabetes for nearly all states with higher prevalences of stroke in the Southeast.

FIGURE 7.

Age-Standardized Trends in Prevalence of Diabetes and Stroke Among Women Age ≥20 Years, U.S., 1988–2023.

Diabetes includes both diagnosed diabetes based on self-report and undiagnosed diabetes based on fasting plasma glucose ≥126 mg/dL and A1C ≥6.5%. Stroke is self-reported. There was an 18-month gap in NHANES data collection between 2020 Q1 and August 2021. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1988–2023

Line graph showing that, among adult women, the prevalence of diabetes has increased between 1988 and 2023 while the prevalence of stroke and having both diabetes and stroke has remained relatively stable over the same time period.

FIGURE 8.

Age-Standardized Trends in Prevalence of Diabetes and Stroke Among Men Age ≥20 Years, U.S., 1988–2023.

Diabetes includes both diagnosed diabetes based on self-report and undiagnosed diabetes based on fasting plasma glucose ≥126 mg/dL and A1C ≥6.5%. Stroke is self-reported. There was an 18-month gap in NHANES data collection between 2020 Q1 and August 2021. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1988–2023

Line graph showing that, among adult men, the prevalence of diabetes has increased between 1988 and 2023 while the prevalence of stroke and having both diabetes and stroke has remained relatively stable over the same time period.

TABLE 1.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, NHIS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | Type 2 Diabetes* | No Diabetes
Total | 8.7 (0.4) | 8.8 (0.4) | 2.4 (0.1)
Age (years)
20–44 | 2.7 (0.9)^1^ | 3.3 (1.1)^1^ | 0.5 (0.1)
45–54 | 4.9 (0.8) | 4.9 (0.8) | 1.7 (0.2)
55–64 | 7.6 (0.8) | 7.6 (0.8) | 3.0 (0.2)
65–74 | 10.6 (0.8) | 10.5 (0.8) | 5.1 (0.3)
75–84 | 13.7 (1.2) | 13.7 (1.2) | 8.5 (0.5)
≥85 | 16.0 (2.4) | 15.7 (2.4) | 11.3 (0.8)
Sex
Men | 8.3 (0.6) | 8.5 (0.6) | 2.3 (0.1)
Women | 9.1 (0.6) | 9.2 (0.6) | 2.4 (0.1)
Race/ethnicity
Non-Hispanic White | 9.3 (0.5) | 9.5 (0.5) | 2.6 (0.1)
Non-Hispanic Black | 9.6 (1.0) | 9.7 (1.0) | 3.0 (0.2)
All Hispanic | 7.6 (1.1) | 7.5 (1.1) | 1.4 (0.1)
Mexican American^†^ | 5.9 (1.2) | 5.9 (1.2) | 1.3 (0.2)
Other Hispanic^†^ | 10.3 (2.0) | 10.0 (2.0) | 1.5 (0.2)
Non-Hispanic Asian | 4.8 (1.3) | 4.8 (1.3) | 1.2 (0.2)
Non-Hispanic American Indian or Alaska Native | 10.6 (3.7)^1^ | 11.6 (4.1)^1^ | 5.3 (0.9)

All data are self-reported.

* Type 2 diabetes is defined as self-report of a physician diagnosis of diabetes, excluding participants with probable type 1 diabetes. Probable type 1 diabetes is defined as self-report of type 1 diabetes, continuous insulin use within 1 year of diagnosis, and current insulin use.

† Mexican American and Other Hispanic are subsets of the All Hispanic category.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Surveys (NHIS) 2022–2023

TABLE 2.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, NHANES, U.S., 2017–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes* | Undiagnosed Diabetes^†^ | Prediabetes^‡^ | Normal Glucose^§^
Total | 10.6 (0.9) | 6.4 (1.3) | 3.3 (0.4) | 1.8 (0.4)
Age (years)
20–44 | 3.7 (1.3)^1^ | ^3^ | ^3^ | 0.5 (0.1)
45–54 | 4.8 (1.0) | ^3^ | 2.4 (0.5) | 2.7 (1.2)^2^
55–64 | 10.2 (1.8) | 1.9 (0.6)^1^ | 4.2 (1.1) | 2.1 (0.8)^1^
65–74 | 16.9 (2.4) | 3.0 (1.3)^2^ | 4.9 (1.2) | ^3^
≥75 | 12.4 (1.6) | 24.0 (7.7)^1^ | 13.1 (1.9) | 4.8 (2.0)^2^
Sex
Men | 10.3 (1.3) | 2.5 (0.8)^1^ | 3.2 (0.6) | 0.9 (0.3)
Women | 10.9 (1.3) | 10.6 (2.4) | 3.4 (0.4) | 2.3 (0.7)^1^
Race/ethnicity
Non-Hispanic White | 11.4 (1.4) | 9.2 (2.4) | 3.7 (0.5) | 1.9 (0.7)^1^
Non-Hispanic Black | 10.9 (1.5) | 5.3 (1.7)^1^ | 4.0 (0.8) | 3.1 (1.0)^1^
All Hispanic | 8.5 (1.5) | ^3^ | 1.3 (0.4) | 1.3 (0.6)^2^
Mexican American^║^ | 7.1 (1.9) | ^3^ | 0.7 (0.3)^2^ | ^3^
Other Hispanic^║^ | 10.0 (2.3) | ^3^ | 2.0 (0.6)^1^ | 1.9 (0.9)^2^
Non-Hispanic Asian | 7.9 (2.5)^1^ | ^3^ | 1.3 (0.5)^2^ | ^3^
Other, including multiracial | 9.8 (2.0) | ^3^ | 6.2 (2.5)^1^ | ^3^

History of stroke and demographic characteristics are self-reported. There was an 18-month gap in NHANES data collection between 2020 Q1 and August 2021. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; FPG, fasting plasma glucose.

* Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional.

† Undiagnosed diabetes is defined as no self-report of diabetes and A1C ≥6.5% or FPG ≥126 mg/dL.

‡ Prediabetes is defined as no self-report of diabetes and A1C 5.7%–<6.5% or FPG 100–<126 mg/dL.

§ Normal glucose is defined as no self-report of diabetes and A1C <5.7% and FPG <100 mg/dL.

║ Mexican American and Other Hispanic are subsets of the All Hispanic category.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2017–2023

TABLE 3.

Incidence of Inpatient Hospital Discharges Listing Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, HCUP-NIS, U.S., 2021

CHARACTERISTICS | INCIDENCE PER 100 (STANDARD ERROR)
CHARACTERISTICS | All Diabetes | Type 2 Diabetes | Type 1 Diabetes | No Diabetes
Total | 4.8 (0.04) | 4.9 (0.04) | 2.2 (0.06) | 3.2 (0.03)
Age (years)
20–44 | 1.8 (0.04) | 2.1 (0.05) | 1.0 (0.06) | 0.7 (0.01)
45–54 | 4.0 (0.06) | 4.0 (0.06) | 2.9 (0.17) | 2.9 (0.04)
55–64 | 4.8 (0.04) | 4.8 (0.05) | 3.4 (0.20) | 3.9 (0.05)
65–74 | 5.2 (0.05) | 5.2 (0.05) | 4.4 (0.25) | 4.6 (0.05)
75–84 | 5.6 (0.06) | 5.6 (0.06) | 5.0 (0.39) | 5.4 (0.06)
≥85 | 6.1 (0.08) | 6.1 (0.08) | 4.7 (0.66) | 6.1 (0.06)
Sex
Men | 4.8 (0.04) | 4.9 (0.04) | 2.4 (0.09) | 3.9 (0.04)
Women | 4.8 (0.04) | 4.6 (0.05) | 2.0 (0.08) | 2.7 (0.03)
Race/ethnicity
White | 4.5 (0.04) | 4.6 (0.04) | 2.3 (0.08) | 3.3 (0.03)
Black | 5.5 (0.07) | 5.7 (0.08) | 1.8 (0.12) | 3.3 (0.06)
Hispanic | 4.6 (0.08) | 4.7 (0.08) | 2.0 (0.17) | 2.1 (0.05)
Asian/Pacific Islander | 6.5 (0.13) | 6.5 (0.14) | 3.3 (0.63) | 3.5 (0.12)
Native American | 3.6 (0.18) | 3.7 (0.19) | 1.4 (0.49)^1^ | 2.2 (0.16)

Diabetes is defined as: all diabetes: ICD-10 codes E10–E14; type 2 diabetes: ICD-10 code E11; type 1 diabetes: ICD-10 code E10. Stroke is defined as Chronic Conditions Warehouse (CCW) for Stroke/Transient Ischemic Attack, at least one inpatient discharge. ICD-10, International Classification of Diseases, Tenth Revision.

^1^ Relative standard error >30%–40%

SOURCE: Healthcare Cost and Utilization Project (HCUP), National Inpatient Sample (NIS) 2021

TABLE 4.

Incidence Rates and Relative Risks of Stroke Subtypes, by Diabetes Status, the Nurses’ Health Study, 1976–2002

VARIABLES | NO DIABETES | TYPE 1 DIABETES | TYPE 2 DIABETES
Total stroke
Cases | 2,384 | 33 | 637
Incidence* | 92 | 475 | 240
Age-adjusted RR | 1.0 | 5.9 (4.2–8.3) | 2.3 (2.1–2.6)
Multivariate-adjusted RR^†^ | 1.0 | 4.7 (3.3–6.6) | 1.8 (1.7–2.0)
Ischemic stroke
Cases | 1,083 | 20 | 373
Incidence* | 42 | 288 | 140
Age-adjusted RR | 1.0 | 7.9 (5.1–12.2) | 3.0 (2.6–3.4)
Multivariate-adjusted RR^†^ | 1.0 | 6.3 (4.0–9.8) | 2.3 (2.0–2.6)
Thrombotic stroke
Cases | 847 | 16 | 313
Incidence* | 33 | 230 | 118
Age-adjusted RR | 1.0 | 8.0 (4.9–13.1) | 3.2 (2.8–3.6)
Multivariate-adjusted RR^†^ | 1.0 | 6.4 (3.9–10.5) | 2.4 (2.1–2.7)
Large-artery occlusive infarction
Cases | 307 | 6 | 95
Incidence* | 12 | 86 | 36
Age-adjusted RR | 1.0 | 8.3 (3.7–18.7) | 2.7 (2.2–3.4)
Multivariate-adjusted RR^†^ | 1.0 | 7.2 (3.2–16.2) | 2.0 (1.6–2.6)
Lacunar infarction
Cases | 325 | 6 | 132
Incidence* | 13 | 86 | 50
Age-adjusted RR | 1.0 | 8.2 (3.7–18.4) | 3.6 (2.9–4.4)
Multivariate-adjusted RR^†^ | 1.0 | 7.2 (3.2–16.1) | 2.8 (2.3–3.5)
Hemorrhagic stroke
Cases | 257 | 3 | 31
Incidence* | 10 | 43 | 12
Age-adjusted RR | 1.0 | 4.5 (1.4–14.1) | 1.1 (0.8–1.6)
Multivariate-adjusted RR^†^ | 1.0 | 3.8 (1.2–11.8) | 1.0 (0.7–1.4)
Stroke of unknown subtype
Cases | 215 | 4 | 88
Incidence* | 8 | 58 | 33
Age-adjusted RR | 1.0 | 7.1 (2.6–19.1) | 3.4 (2.6–4.3)
Multivariate-adjusted RR^†^ | 1.0 | 4.7 (1.7–12.7) | 2.3 (1.7–3.0)

Data are presented as Ns or relative risk (RR; 95% confidence interval).

* Incidence rate per 100,000 person-years

† Values were calculated by Cox proportional hazards model adjusted for age, body mass index (BMI, kg/m^2^), physical activity, menopausal status and estrogen use, smoking and hypertension, high cholesterol, ischemic heart disease, aspirin use, and alcohol consumption.

TABLE 5.

Incidence of Ischemic Stroke, by Diabetes Status, Age, and Race, Greater Cincinnati/Northern Kentucky Stroke Study

AGE (YEARS) | AFRICAN AMERICAN | | | WHITE
AGE (YEARS) | Incidence (95% CI) | | IRR | Incidence (95% CI) | | IRR
AGE (YEARS) | Diabetes | No Diabetes | IRR | Diabetes | No Diabetes | IRR
20–44* | 177 (84–271) n=14^†^ | 24 (18–31) n=55 | 7.4 (3.0–11.8) | 128 (79–177) n=26^†^ | 9 (8–11) n=112 | 14.2 (8.0–20.4)
45–54* | 630 (459–800) n=54 | 161 (129–193) n=99 | 3.9 (2.6–5.2) | 395 (307–482) n=80 | 51 (44–57) n=216 | 7.7 (5.8–9.6)
55–64* | 949 (743–1,155) n=84 | 309 (251–367) n=110 | 3.1 (2.2–3.9) | 682 (589–775) n=207 | 135 (122–149) n=370) | 5.0 (4.2–5.9)
65–74* | 1,580 (1,297–1,862) n=120 | 534 (441–627) n=129 | 3.0 (2.2–3.7) | 1,078 (966–1,191) n=353 | 364 (337–391) n=705 | 3.0 (2.6–3.3)
≥75* | 1,453 (1,146–1,761) N=86 | 1,006 (863–1,149) n=193 | 1.4 (1.1–1.8) | 2,215 (2,027–2,404) n=535 | 877 (834–920) n=1,619 | 2.5 (2.3–2.8)
All ages^‡^ | 617 (544–691) n=358 | 233 (215–252) n=586 | 2.6 (2.3–3.0) | 560 (522–598) n=1,201 | 162 (157–167) n=3,022 | 3.5 (3.2–3.7)

Incidence is reported as per 100,000 person-years. Data were combined from study periods July 1993–May 1994, 1999, and 2005. CI, confidence interval; IRR, incidence rate ratio.

* Sex-adjusted to the 2000 U.S. population

† Rates based on samples of <30 should be treated with caution.

‡ Sex- and age-adjusted to the 2000 U.S. population

TABLE 6.

Crude Incidence Rates and Incidence Rate Ratios for Each Race-Sex Group Stratified by Age, the REGARDS Study

RACE-SEX GROUP AND DIABETES STATUS | n/N* | PERSON-YEARS | IR^†^ | 95% CI | IRR^‡^ | 95% CI
Age <65 Years at Baseline
White women
No diabetes | 38/3,296 | 30,818.08 | 1.23 | 0.90–1.69 | - | -
Diabetes | 18/373 | 3,221.89 | 5.59 | 3.53–8.84 | 4.53 | 2.59–7.91
Black women
No diabetes | 53/2,359 | 20,687.66 | 2.56 | 1.96–3.35 | - | -
Diabetes | 34/784 | 6,476.72 | 5.25 | 3.75–7.34 | 2.05 | 1.33–3.15
White men
No diabetes | 63/2,795 | 27,386.11 | 2.30 | 1.80–2.95 | - | -
Diabetes | 25/459 | 4,186.01 | 5.97 | 4.03–8.86 | 2.59 | 1.63–4.13
Black men
No diabetes | 48/1,360 | 11,824.12 | 4.06 | 3.06–5.38 | - | -
Diabetes | 23/477 | 4,098.58 | 5.61 | 3.72–8.46 | 1.38 | 0.84–2.28
Age ≥65 Years at Baseline
White women
No diabetes | 158/2,882 | 25,358.3 | 6.23 | 5.33–7.28 | - | -
Diabetes | 38/418 | 3,174.31 | 11.97 | 8.72–16.43 | 1.92 | 1.35–2.74
Black women
No diabetes | 112/1,740 | 14,710.27 | 7.61 | 6.32–9.17 | - | -
Diabetes | 47/723 | 5,572.04 | 8.44 | 6.35–11.21 | 1.11 | 0.79–1.56
White men
No diabetes | 221/3,092 | 27,339.94 | 8.08 | 7.08–9.22 | - | -
Diabetes | 42/668 | 5,142.82 | 8.17 | 6.03–11.06 | 1.01 | 0.73–1.41
Black men
No diabetes | 56/1,079 | 8,970.31 | 6.24 | 4.80–8.12 | - | -
Diabetes | 42/497 | 3,755.05 | 11.18 | 8.25–15.16 | 1.79 | 1.20–2.68

CI, confidence interval.

* n in the numerator is total stroke events in each group; N in the denominator is total individuals in the corresponding group.

† Incidence rate per 1,000 person-years

‡ Incidence rate ratio

TABLE 7.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, BRFSS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | No Diabetes
Total | 9.5 (0.2) | 2.7 (0.04)
Age (years)
20–44 | 4.7 (0.6) | 0.8 (0.04)
45–54 | 6.9 (0.4) | 2.5 (0.1)
55–64 | 9.9 (0.4) | 3.9 (0.1)
65–74 | 11.1 (0.4) | 5.2 (0.1)
75–79 | 11.7 (0.6) | 6.8 (0.2)
≥80 | 12.3 (0.6) | 9.4 (0.3)
Sex
Men | 9.5 (0.3) | 2.7 (0.1)
Women | 9.5 (0.3) | 2.8 (0.1)
Race/ethnicity
Non-Hispanic White | 9.6 (0.2) | 3.0 (0.04)
Non-Hispanic Black | 11.6 (0.5) | 3.8 (0.2)
All Hispanic | 7.8 (0.5) | 1.6 (0.1)
Non-Hispanic Asian | 6.3 (1.1) | 1.1 (0.2)
Non-Hispanic Native Hawaiian/ Other Pacific Islander | 8.0 (1.7) | 2.2 (0.5)
Non-Hispanic American Indian or Alaska Native | 9.4 (1.0) | 5.2 (0.5)
Non-Hispanic Multiracial | 12.2 (1.5) | 3.3 (0.3)
Non-Hispanic Other Race | 12.6 (2.9) | 4.2 (0.6)

All data are self-reported. Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional.

SOURCE: Behavioral Risk Factor Surveillance System (BRFSS) 2022–2023

TABLE 8.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status and Social Determinants of Health, NHIS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | Type 2 Diabetes* | No Diabetes
Total | 8.7 (0.4) | 8.8 (0.4) | 2.4 (0.1)
Education
Less than high school | 10.7 (1.3) | 10.7 (1.3) | 4.5 (0.3)
High school/GED | 9.7 (0.7) | 9.8 (0.8) | 2.9 (0.1)
More than high school | 7.3 (0.5) | 7.4 (0.5) | 1.9 (0.1)
Poverty income ratio^†^
<1.00 | 13.2 (1.3) | 13.1 (1.4) | 4.7 (0.3)
1.00–2.99 | 9.9 (0.7) | 10.1 (0.7) | 3.1 (0.1)
3.00–4.99 | 7.2 (0.8) | 7.4 (0.8) | 2.1 (0.1)
≥5.00 | 4.8 (0.6) | 4.8 (0.6) | 1.3 (0.1)
Insurance status
Any insurance | 8.9 (0.4) | 9.1 (0.4) | 2.5 (0.1)
Private | 5.2 (0.4) | 5.3 (0.4) | 1.5 (0.1)
Medicare | 12.8 (0.7) | 12.7 (0.7) | 7.1 (0.2)
Medicaid | 14.0 (1.3) | 14.3 (1.3) | 3.9 (0.3)
Urban-rural county-level classification of residence^‡^
Metropolitan
Large central metro | 8.3 (0.8) | 8.2 (0.8) | 1.9 (0.1)
Large fringe metro | 8.1 (0.9) | 8.4 (0.9) | 2.2 (0.1)
Medium and small metro | 9.0 (0.7) | 9.2 (0.7) | 2.7 (0.2)
Nonmetropolitan | 9.6 (0.9) | 9.7 (1.0) | 3.2 (0.2)

All data are self-reported. GED, general equivalency diploma; MSA, metropolitan statistical area.

* Type 2 diabetes is defined as self-report of a physician diagnosis of diabetes, excluding participants with probable type 1 diabetes. Probable type 1 diabetes is defined as self-report of type 1 diabetes, continuous insulin use within 1 year of diagnosis, and current insulin use.

† The poverty income ratio is defined as total family income divided by the poverty threshold for the family’s size.

‡ Large central metro are counties in MSAs of 1 million or more population that (1.) contain the entire population of the largest principal city of the MSA, (2.) are completely contained in the largest principal city of the MSA, or (3.) contain at least 250,000 residents of any principal city of the MSA. Large fringe metro are counties in MSAs of 1 million or more population that do not qualify as large central. Medium and small metro are counties in MSAs of 250,000 to 999,999 population or in MSAs of less than 250,000 population. Nonmetropolitan are counties in micropolitan statistical areas and non-core counties.

SOURCE: National Health Interview Surveys (NHIS) 2022–2023

TABLE 9.

Clinical Studies: Primary Stroke Prevention in Persons With Diabetes

STUDY, YEARS OF DATA COLLECTION (REF.) | POPULATION | INTERVENTION | MAIN RESULTS
Glucose Control Studies
United Kingdom Prospective Diabetes Study (UKPDS), 1977–1997 (206) | Newly diagnosed type 2 diabetes | Intensive glucose control with sulfonylureas or insulin versus diet therapy | Intensive blood glucose-lowering therapy reduced the risk of microvascular (retinal) disease but not of macrovascular disease, including overall stroke risk. The study did not separately assess the risks of small artery and large artery subtypes of stroke.
Action to Control Cardiovascular Risk in Diabetes (ACCORD), 2001–2007 (209) | Type 2 diabetes, average duration 10 years, plus mean A1C 8.1% | Intensive glucose control with an A1C target <6% versus standard glucose control with an A1C target 7.0%–7.9% for CVD and CVD mortality | No benefit of intensive glucose control was seen for stroke events. Trial was stopped due to increased mortality in the intensive arm.
Action in Diabetes and Vascular Disease: Preterax and Diamicron MR Controlled Evaluation (ADVANCE), 2001–2007 (210) | Type 2 diabetes, average duration 8 years, plus mean A1C 7.2% | Intensive glucose control with an A1C target ≤6.5% versus standard glucose control with an A1C target 7.0% for microvascular and macrovascular outcomes | No difference was found between the two arms. Severe hypoglycemia was observed in the intensive arm.
Veterans Affairs Diabetes Trial (VADT), 2000–2008 (211) | Poorly controlled type 2 diabetes, plus mean A1C 9.5% | Intensive versus standard glucose control | No difference was found between the arms. Less progression to albuminuria was seen with intensive control.
Diabetes Control and Complications Trial (DCCT), 1983–1993 (212) | Type 1 diabetes | Intensive glucose control with A1C ≤6.0% and glucose levels 70–120 mg/dL versus standard glucose control | No difference was found between the arms.
Trial to Evaluate Cardiovascular and Other Long-term Outcomes With Semaglutide in Subjects With Type 2 Diabetes (SUSTAIN-6), 2013–2016 (220) | Type 2 diabetes and preexisting CVD, HF, or CKD at age ≥50 years or CV risk at age ≥60 years; mean baseline A1C 8.7%; 11.6% ischemic stroke and 3.3% hemorrhagic stroke | Semaglutide subcutaneous injection versus placebo | Significant nonfatal stroke reduction of 39%
Researching Cardiovascular Events With a Weekly Incretin in Diabetes (REWIND), 2011–2018 (221) | Type 2 diabetes and prior ASCVD event or risk factors for ASCVD; mean baseline A1C 7.4%; 6.9% stroke; 9.1% stroke or TIA | Dulaglutide subcutaneous injection versus placebo | • Significant total stroke (nonfatal or fatal stroke) reduction of 24%; significant nonfatal stroke reduction of 24%; significant disabling stroke reduction of 26%; significant ischemic stroke reduction of 25%; significant nonfatal stroke or all-cause death reduction of 12%. • Primary stroke prevention: significant total stroke (nonfatal or fatal stroke) reduction of 22% in patients without previous stroke or TIA.
Blood Pressure Control Studies
Systolic Hypertension in the Elderly Program Cooperative Research Group Trial (SHEP), 1985–1991 (228) | Elderly population with type 2 diabetes and isolated hypertension | Low-dose diuretic with or without beta blocker or reserpine for CVD | 20% reduction of stroke events with control of isolated systolic hypertension
United Kingdom Prospective Diabetes Study (UKPDS), 1977–1997 (229) | Newly diagnosed type 2 diabetes | Prospective observation | Every 10 mmHg reduction in systolic blood pressure reduced the risk of ischemic stroke by approximately 20%.
MICRO Heart Outcomes Prevention Evaluation Study (MICRO-HOPE), not reported (230) | High-risk patients with type 2 diabetes and coronary artery disease | Addition of an ACEI to any current medical therapy for CVD | Stroke reduction of 33%
Losartan Intervention for Endpoint Reduction in Hypertension Trial (LIFE), 1995–2001 (231) | High-risk patients with diabetes, severe hypertension, and left ventricular hypertrophy | Comparison of angiotensin receptor blocker (ARB) versus beta blocker on CVD | 24% reduction of major vascular events with losartan; nonsignificant 20% reduction of stroke
Action in Diabetes and Vascular Disease: Preterax and Diamicron MR Controlled Evaluation Trial (ADVANCE), 2001–2007 (232) | Type 2 diabetes | ACEI (perindopril) plus thiazide diuretic (indapamide) versus placebo for prevention of microvascular and macrovascular outcomes | 9% of all vascular events; relative reductions for macrovascular outcomes alone, including the risk of stroke, were nonsignificant.
Lipid Control Study
Collaborative Atorvastatin Diabetes Study (CARDS), 1997–2001 (143) | Type 2 diabetes, an LDL cholesterol level ≤160 mg/dL, plus one additional risk factor | Atorvastatin 10 mg/day or placebo for primary stroke prevention | 48% reduction in stroke risk with atorvastatin

Conversion formulas for A1C, cholesterol, and glucose values are available in the Conversions section. A1C, glycated hemoglobin; ACEI, angiotensin-converting enzyme inhibitor; ASCVD, atherosclerotic cardiovascular disease; CKD, chronic kidney disease; CV, cardiovascular; CVD, cardiovascular disease; HF, heart failure; LDL, low-density lipoprotein; TIA, transient ischemic attack.

SOURCE: References are listed within the table.

TABLE 10.

Clinical Studies: Secondary Stroke Prevention in Persons With Diabetes

STUDY, YEARS OF DATA COLLECTION (REF.) | POPULATION | INTERVENTION | MAIN RESULTS
Insulin Resistance Intervention after Stroke Trial (IRIS), 2005–2013 (216) | Patients with recent stroke/TIA plus insulin resistance, but no diabetes | Pioglitazone 45 mg/day or placebo for secondary stroke prevention | Stroke reduction of 24%
Trial to Evaluate Cardiovascular and Other Long-term Outcomes With Semaglutide in Subjects With Type 2 Diabetes (SUSTAIN-6), 2013–2016 (220) | Type 2 diabetes and preexisting CVD, HF, or CKD at age ≥50 years or CV risk at age ≥60 years; mean baseline A1C 8.7%; 11.6% ischemic stroke and 3.3% hemorrhagic stroke | Semaglutide subcutaneous injection versus placebo | Significant nonfatal stroke reduction of 39%
Researching Cardiovascular Events With a Weekly Incretin in Diabetes (REWIND), 2011–2018 (221) | Type 2 diabetes and prior ASCVD event or risk factors for ASCVD; mean baseline A1C 7.4%; 6.9% stroke; 9.1% stroke or TIA | Dulaglutide subcutaneous injection versus placebo | • Significant total stroke (nonfatal or fatal stroke) reduction of 24%; significant nonfatal stroke reduction of 24%; significant disabling stroke reduction of 26%; significant ischemic stroke reduction of 25%; significant nonfatal stroke or all-cause death reduction of 12%. • Secondary stroke prevention: nonsignificant total stroke (nonfatal or fatal stroke) reduction of 26% in patients with previous stroke or TIA.
Stroke Prevention by Aggressive Reduction in Cholesterol Levels trial (SPARCL), 1998–2001 (233) | Patients with prior stroke and type 2 diabetes or the metabolic syndrome | Atorvastatin 80 mg/day or placebo for secondary stroke prevention | Atorvastatin did not show any effect on reduction of vascular events.

A conversion formula for A1C values is available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease; CKD, chronic kidney disease; CV, cardiovascular; CVD, cardiovascular disease; HF, heart failure; TIA, transient ischemic attack.

SOURCE: References are listed within the table.

TABLE 11.

Risk Factor Management for Primary Prevention of Stroke in Persons With Diabetes

RISK FACTOR | RECOMMENDATIONS FOR THE GENERAL POPULATION* | RECOMMENDATIONS FOR PERSONS WITH DIABETES†
Hypertension | • In adults with stage 2 hypertension or stage 1 hypertension with a higher risk for ASCVD, lifestyle improvement and antihypertensive drug treatment to an SBP/DBP <130/80 mmHg are recommended to prevent stroke. (Class I; Level of Evidence A) • In adults with hypertension, thiazide and thiazide-like diuretics, calcium channel blockers, ACEIs, and ARBs are recommended as initial antihypertensive drug therapies to prevent stroke. (Class I; Level of Evidence A) • In most adults with hypertension, antihypertensive drug treatment, incorporating ≥2 antihypertensive medications, is indicated to achieve the blood pressure control necessary to prevent stroke. (Class I; Level of Evidence A) | • People with diabetes who have hypertension should be treated to blood pressure targets of <130/80 mmHg. (Level of Evidence B) This recommendation is consistent with guidelines from the American College of Cardiology (ACC) (2018) and American Heart Association (AHA) (2017), the International Society of Hypertension (2020), and the European Society of Cardiology (2018). • For people with blood pressure >120/80 mmHg, lifestyle intervention consists of weight loss when indicated, a Dietary Approaches to Stop Hypertension (DASH)-style eating pattern, including reducing sodium and increasing potassium intake, moderation of alcohol intake, and increased physical activity. (Level of Evidence A) • Individuals with confirmed office-based blood pressure ≥130/80 mmHg qualify for initiation and titration of pharmacologic therapy to achieve the recommended blood pressure goal of <130/80 mmHg. ACEI or ARBs are recommended first-line therapy for hypertension in people with diabetes and coronary artery disease. (Level of Evidence A)
Dyslipidemia | • In adults age 20–75 years with LDL cholesterol level >190 mg/dL (>4.9 mmol/L), 10-year ASCVD risk ≥20%, or 10-year ASCVD risk ≥7.5%–<20% plus ≥1 risk enhancers, treatment with a statin is recommended to reduce the risk of a first stroke. (Class I; Level of Evidence A) • In adults age 20–75 years without CVD with LDL cholesterol level >190 mg/dL (>4.9 mmol/L), 10-year ASCVD risk ≥20%, or 10-year ASCVD risk ≥7.5%–<20% plus ≥1 risk enhancers, who cannot reach goals or cannot tolerate other therapies, such as statins, the benefit of treatment with alirocumab or evolocumab compared with other active lipid-lowering therapy for the reduction of the risk of a first stroke is uncertain. (Class IIb; Level of Evidence A) • In adults who do not tolerate statin therapy and who have LDL cholesterol >100 mg/dL (>2.6 mmol/L) and elevated cardiovascular risk, treatment with bempedoic acid to reduce the risk of a first stroke is not well established. (Class IIb; Level of Evidence B-R) • In adults with moderate or low intake of long-chain omega-3 fatty acid, supplementation is not recommended to reduce the risk of a first stroke. (Class III; Level of Evidence A) | • For people with diabetes age 40–75 years without ASCVD, use moderate-intensity statin therapy in addition to lifestyle therapy. (Level of Evidence A) • For people with diabetes age 40–75 years at higher cardiovascular risk, including those with one or more additional ASCVD risk factors, high-intensity statin therapy is recommended to reduce LDL cholesterol by 50% of baseline and to obtain an LDL cholesterol goal of <70 mg/dL (<1.8 mmol/L). (Level of Evidence A) • For people with diabetes age 40–75 years at higher cardiovascular risk, especially those with multiple additional ASCVD risk factors and an LDL cholesterol ≥70 mg/dL (≥1.8 mmol/L), it may be reasonable to add ezetimibe or a PCSK9 inhibitor to maximum tolerated statin therapy. (Level of Evidence B) • For people with diabetes age 20–39 years with additional ASCVD risk factors, it may be reasonable to initiate statin therapy in addition to lifestyle therapy. (Level of Evidence C) • For people with diabetes age >75 years already on statin therapy, it is reasonable to continue statin treatment. (Level of Evidence B) For people with diabetes age >75 years, it may be reasonable to initiate moderate-intensity statin therapy after discussion of potential benefits and risks. (Level of Evidence C) • In people with diabetes intolerant to statin therapy, treatment with bempedoic acid is recommended to reduce cardiovascular event rates as an alternative cholesterol-lowering plan. (Level of Evidence A) • Intensify lifestyle therapy and optimize glycemic control for patients with elevated triglyceride levels (≥150 mg/dL [≥1.7 mmol/L]) and/or low HDL cholesterol (<40 mg/dL [<1.0 mmol/L] for men, <50 mg/dL [<1.3 mmol/L] for women). (Level of Evidence C)
Hyperglycemia | No recommendation | • In patients with diabetes and high cardiovascular risk or established CVD and A1C ≥7%, treatment with a GLP-1 receptor agonist is effective to reduce the risk of stroke. (Class I; Level of Evidence A) • In patients with type 1 diabetes or type 2 diabetes, intensive glycemic control (targeting A1C ≤6.5%) is not beneficial for stroke prevention.
Atrial fibrillation (AF) | • For patients with AF and an elevated CHA2DS2-VASc score of ≥2 in men or ≥3 in women, oral anticoagulants are recommended. Options include: warfarin, dabigatran, rivaroxaban, apixaban, or edoxaban. (Class I; Level of Evidence A) • NOACs (dabigatran, rivaroxaban, apixaban, and edoxaban) are recommended over warfarin in NOAC-eligible patients with AF (except with moderate-to-severe mitral stenosis or a mechanical heart valve). (Class I; Level of Evidence A) | No recommendation
Smoking | • For patients who are nonusers of tobacco products, continued complete abstention from cigarette smoking, in addition to other tobacco products and electronic nicotine delivery systems, and avoidance of exposure to environmental tobacco smoke (secondhand smoke exposure) are recommended to avoid the associated increased risk of stroke. (Class I; Level of Evidence B-NR) • For patients who are active cigarette smokers, smoking cessation pharmacotherapy delivered along with behavioral counseling is recommended, in preference to behavioral counseling alone, to facilitate smoking cessation. (Class I; Level of Evidence A) | • Advise all individuals not to use cigarettes and other tobacco products or e-cigarettes. (Level of Evidence A) • After identification of tobacco or e-cigarette use, include smoking cessation counseling and other forms of treatment as a routine component of diabetes care. (Level of Evidence A)
Obesity/diet | • In adults without prior CVD and who are at high or intermediate CVD risk, a Mediterranean diet is recommended to reduce the risk of incident stroke. (Class I; Level of Evidence BR) • In adults who are age ≥60 years and have uncontrolled blood pressure (SBP ≥140 mmHg if taking antihypertensive medication or ≥160 mmHg if not), compared with using 100% sodium chloride, salt substitution (75% sodium chloride and 25% potassium chloride) is reasonable to reduce the risk of incident stroke. (Class IIa; Level of Evidence BR) • In patients with class II obesity (BMI 35–39.9 kg/m^2^) or greater, bariatric surgical procedures to promote weight loss may be considered to reduce the risk of stroke. (Class IIb; Level of Evidence C-LD) | • In people with type 2 diabetes and overweight or obesity, weight management should represent a primary goal of treatment along with glycemic management. (Level of Evidence B) • Provide weight management treatment, aiming for any magnitude of weight loss. Weight loss of 3%–7% of baseline weight improves glycemia and other intermediate cardiovascular risk factors. (Level of Evidence A) • Sustained loss of >10% of body weight usually confers greater benefits, including disease-modifying effects and possible remission of type 2 diabetes, and may improve long-term cardiovascular outcomes and mortality. (Level of Evidence B) • Consider metabolic surgery as a weight and glycemic management approach in people with diabetes with BMI ≥30.0 kg/m^2^ (or ≥27.5 kg/m^2^ in Asian American individuals) who are otherwise good surgical candidates. (Level of Evidence A) • Lifestyle modification focusing on weight loss (if indicated); application of a Mediterranean or DASH eating pattern; reduction of saturated fat and trans fat; increase of dietary n-3 fatty acids, viscous fiber, and plant stanol and sterol intake; and increased physical activity should be recommended to improve the lipid profile and reduce the risk of developing ASCVD in people with diabetes. (Level of Evidence A)
Physical inactivity | • In adults, counseling patients to engage in at least 150 minutes of moderate-intensity physical activity, 75 minutes of vigorous-intensity physical activity, or an equivalent combination per week is recommended to reduce the risk of stroke. (Class I; Level of Evidence C-LD) • In adults, counseling to avoid excessive time spent in sedentary behavior (characterized by low energy expenditure while sitting, reclining, or lying while awake) is recommended to reduce the risk of stroke. (Class I; Level of Evidence C-LD) | • Counsel youth with type 1 diabetes (Level of Evidence C) or type 2 diabetes (Level of Evidence B) to engage in 60 minutes per day or more of moderate- or vigorous-intensity aerobic activity, with muscle-strengthening and bone-strengthening activities at least three days per week, and to limit the amount of time being spent sedentary, including recreational screen time. (Level of Evidence C) • For adults with diabetes, the recommendation is the same as the general population. Adults with type 1 diabetes (Level of Evidence C) and type 2 diabetes (Level of Evidence B) should engage in two to three sessions per week of resistance exercise on nonconsecutive days.
Obstructive sleep apnea (OSA) | In patients with OSA, continuous positive airway pressure (CPAP) might be reasonable to reduce the risk of stroke. (Class IIb; Level of Evidence C-LD) | No recommendation

Recommendations for control of vascular risk factors for primary and secondary stroke prevention are based on the American Heart Association (AHA)/American Stroke Association (ASA), and American Diabetes Association (ADA) guidelines. Conversion formulas for A1C, cholesterol, and triglyceride values are available in the Conversions section. A1C, glycated hemoglobin; ACEI, angiotensin-converting enzyme inhibitor; AF, atrial fibrillation; ARB, angiotensin receptor blocker; ASCVD, atherosclerotic cardiovascular disease; BMI, body mass index; CVD, cardiovascular disease; DASH, Dietary Approaches to Stop Hypertension; DBP, diastolic blood pressure; GLP-1, glucagon-like peptide-1; HDL, high-density lipoprotein; LDL, low-density lipoprotein; NOAC, novel oral anticoagulant; OSA, obstructive sleep apnea; PCSK9, proprotein convertase subtilisin/kexin type 9; RCT, randomized controlled trial; SBP, systolic blood pressure.

* Class (strength) of evidence: I=strong (benefit>>>risk); IIa=moderate (benefit>>risk); IIb=weak (benefit≥risk); III=no benefit or harm. Level of evidence: A=high-quality evidence from more than one RCT, meta-analyses of high-quality RCTs, or one or more RCTs corroborated by evidence from high-quality registry studies; BR=moderate-quality evidence from one or more RCT, or meta-analyses of moderate-quality RCTs; B-NR=moderate-quality evidence from one or more well-designed, well-executed nonrandomized studies, observational studies, or registry studies, or meta-analyses of such studies; C-LD=randomized or nonrandomized observational registry studies with limitation of design or execution, meta-analyses of such studies, or physiological of mechanistic studies in human subjects.

† Level of evidence: A=clear evidence from well-conducted, generalizable RCTs; B=supportive evidence from well-conducted cohort studies; C=supportive evidence from poorly controlled or uncontrolled studies.

SOURCE: References (222,223,224,225,226,227)

## Appendices

APPENDIX TABLE A1.

Age-Standardized Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, NHIS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | Type 2 Diabetes* | No Diabetes
Total | 8.7 (0.4) | 8.7 (0.4) | 4.2 (0.1)
Age (years)
20–44 | 2.7 (0.9)^1^ | 3.3 (1.1)^1^ | 0.5 (0.1)
45–54 | 4.9 (0.8) | 4.9 (0.8) | 1.7 (0.2)
55–64 | 7.6 (0.8) | 7.6 (0.8) | 3.0 (0.2)
65–74 | 10.6 (0.8) | 10.5 (0.8) | 5.1 (0.3)
75–84 | 13.7 (1.2) | 13.7 (1.2) | 8.5 (0.5)
≥85 | 16.0 (2.4) | 15.7 (2.4) | 11.3 (0.8)
Sex
Men | 8.4 (0.6) | 8.4 (0.6) | 4.3 (0.2)
Women | 9.0 (0.6) | 9.0 (0.6) | 4.1 (0.2)
Race/ethnicity
Non-Hispanic White | 8.9 (0.5) | 9.0 (0.5) | 4.1 (0.1)
Non-Hispanic Black | 9.8 (1.0) | 9.8 (1.0) | 6.0 (0.5)
All Hispanic | 8.2 (1.2) | 8.1 (1.2) | 3.6 (0.4)
Mexican American^†^ | 6.5 (1.4) | 6.5 (1.4) | 3.8 (0.7)
Other Hispanic^†^ | 10.4 (2.0) | 10.0 (2.0) | 3.5 (0.5)
Non-Hispanic Asian | 4.6 (1.2) | 4.6 (1.2) | 2.4 (0.5)
Non-Hispanic American Indian or Alaska Native | 12.2 (3.8)^1^ | 12.7 (4.0)^1^ | 9.2 (1.4)

All data are self-reported. Data are age-standardized to the NHIS 2022–2023 population with diabetes, using age categories 20–44, 45–64, and ≥65 years.

* Type 2 diabetes is defined as self-report of a physician diagnosis of diabetes, excluding participants with probable type 1 diabetes. Probable type 1 diabetes is defined as self-report of type 1 diabetes, continuous insulin use within 1 year of diagnosis, and current insulin use.

† Mexican American and Other Hispanic are subsets of the All Hispanic category.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Surveys (NHIS) 2022–2023

APPENDIX TABLE A2.

Age-Standardized Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, NHANES, U.S., 2017–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes* | Undiagnosed Diabetes^†^ | Prediabetes^‡^ | Normal Glucose^§^
Total | 10.8 (0.9) | 7.8 (1.6) | 5.1 (0.5) | 5.3 (2.0)^1^
Age (years)
20–44 | 3.7 (1.3)^1^ | ^3^ | ^3^ | 0.5 (0.1)
45–54 | 4.8 (1.0) | ^3^ | 2.4 (0.5) | 2.7 (1.2)^2^
55–64 | 10.2 (1.8) | 1.9 (0.6)^1^ | 4.2 (1.1) | 2.1 (0.8)^1^
65–74 | 16.9 (2.4) | 3.0 (1.3)^2^ | 4.9 (1.2) | ^3^
≥75 | 12.4 (1.6) | 24.0 (7.7)^1^ | 13.1 (1.9) | 4.8 (2.0)^2^
Sex
Men | 10.5 (1.2) | 3.4 (1.1)^1^ | 5.9 (1.2) | 3.2 (0.7)
Women | 11.1 (1.3) | 12.3 (2.7) | 4.6 (0.5) | 6.4 (2.9)^2^
Race/ethnicity
Non-Hispanic White | 11.2 (1.3) | 9.4 (2.5) | 4.9 (0.6) | ^3^
Non-Hispanic Black | 11.4 (1.4) | 8.2 (2.9)^1^ | 6.2 (1.2) | 8.9 (3.0)^1^
All Hispanic | 9.4 (1.7) | ^3^ | 2.9 (0.9)^1^ | 6.6 (3.1)^2^
Mexican American^║^ | 8.7 (2.4) | ^3^ | ^3^ | ^3^
Other Hispanic^║^ | 10.3 (2.5) | ^3^ | 3.5 (1.2)^2^ | ^3^
Non-Hispanic Asian | 8.4 (2.7)^1^ | ^3^ | 3.0 (1.2)^1^ | ^3^
Other, including multiracial | 10.7 (2.3) | ^3^ | 12.5 (4.8)^1^ | ^3^

History of stroke and demographic characteristics are self-reported. There was an 18-month gap in NHANES data collection between 2020 Q1 and August 2021. Data are age-standardized to the National Health Interview Survey (NHIS) 2022–2023 population with diabetes, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; FPG, fasting plasma glucose.

* Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional.

† Undiagnosed diabetes is defined as no self-report of diabetes and A1C ≥6.5% or FPG ≥126 mg/dL.

‡ Prediabetes is defined as no self-report of diabetes and A1C 5.7%–<6.5% or FPG 100–<126 mg/dL.

§ Normal glucose is defined as no self-report of diabetes and A1C <5.7% and FPG <100 mg/dL.

║ Mexican American and Other Hispanic are subsets of the All Hispanic category.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2017–2023

APPENDIX TABLE A3.

Age-Standardized Incidence of Inpatient Hospital Discharges Listing Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, HCUP-NIS, U.S., 2021

CHARACTERISTICS | INCIDENCE PER 100 (STANDARD ERROR)
CHARACTERISTICS | All Diabetes | Type 2 Diabetes | Type 1 Diabetes | No Diabetes
Total | 4.6 (0.04) | 4.7 (0.04) | 3.6 (0.11) | 4.0 (0.04))
Age (years)
20–44 | 1.8 (0.04) | 2.1 (0.05) | 1.0 (0.06) | 0.7 (0.01)
45–54 | 4.0 (0.06) | 4.0 (0.06) | 2.9 (0.17) | 2.9 (0.04)
55–64 | 4.8 (0.05) | 4.8 (0.05) | 3.4 (0.20) | 3.9 (0.05)
65–74 | 5.2 (0.05) | 5.2 (0.05) | 4.4 (0.25) | 4.6 (0.05)
75–84 | 5.6 (0.06) | 5.6 (0.06) | 5.0 (0.39) | 5.4 (0.06)
≥85 | 6.1 (0.08) | 6.1 (0.08) | 4.7 (0.66) | 6.1 (0.06)
Sex
Men | 4.6 (0.04) | 4.7 (0.04) | 3.9 (0.17) | 4.2 (0.04)
Women | 4.6 (0.04) | 4.6 (0.04) | 3.3 (0.15) | 3.8 (0.04)
Race/ethnicity
White | 4.2 (0.04) | 4.3 (0.04) | 3.4 (0.12) | 3.7 (0.04)
Black | 5.5 (0.07) | 5.6 (0.07) | 4.1 (0.37) | 5.0 (0.07)
Hispanic | 4.6 (0.08) | 4.7 (0.08) | 4.8 (0.52) | 3.8 (0.07)
Asian/Pacific Islander | 6.2 (0.14) | 6.2 (0.14) | 5.1 (1.09) | 5.8 (0.14)
Native American | 3.8 (0.20) | 3.9 (0.20) | ^1^ | 3.5 (0.23)

Data are age-standardized to the National Health Interview Survey (NHIS) 2022–2023 population with diabetes, using age categories 20–44, 45–64, and ≥65 years. Diabetes is defined as: all diabetes: ICD-10 codes E10–E14; type 2 diabetes: ICD-10 code E11; type 1 diabetes: ICD-10 code E10. Stroke is defined as Chronic Conditions Warehouse (CCW) for Stroke/Transient Ischemic Attack, at least one inpatient discharge. ICD-10, International Classification of Diseases, Tenth Revision.

^1^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: Healthcare Cost and Utilization Project (HCUP), National Inpatient Sample (NIS) 2021

APPENDIX TABLE A4.

Age-Standardized Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, BRFSS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | No Diabetes
Total | 9.5 (0.2) | 4.4 (0.1)
Age (years)
20–44 | 4.7 (0.6) | 0.8 (0.0)
45–54 | 6.9 (0.4) | 2.5 (0.1)
55–64 | 9.9 (0.4) | 3.9 (0.1)
65–74 | 11.1 (0.4) | 5.2 (0.1)
75–79 | 11.7 (0.6) | 6.8 (0.2)
≥80 | 12.3 (0.6) | 9.4 (0.3)
Sex
Men | 9.6 (0.3) | 4.6 (0.1)
Women | 9.5 (0.3) | 4.3 (0.1)
Race/ethnicity
Non-Hispanic White | 9.3 (0.2) | 4.3 (0.1)
Non-Hispanic Black | 11.8 (0.5) | 6.3 (0.3)
All Hispanic | 7.9 (0.5) | 3.3 (0.2)
Non-Hispanic Asian | 6.5 (1.2) | 2.3 (0.4)
Non-Hispanic Native Hawaiian/ Other Pacific Islander | 9.4 (2.1) | 5.5 (1.9)^1^
Non-Hispanic American Indian or Alaska Native | 10.2 (1.1) | 8.0 (0.9)
Non-Hispanic Multiracial | 13.3 (1.7) | 7.5 (0.7)
Non-Hispanic Other Race | 12.5 (2.8) | 6.1 (0.9)

All data are self-reported. Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional. Data are age-standardized to the National Health Interview Survey (NHIS) 2022–2023 population with diabetes, using age categories 20–44, 45–64, and ≥65 years.

^1^ Relative standard error >30%–40%

SOURCE: Behavioral Risk Factor Surveillance System (BRFSS) 2022–2023

APPENDIX TABLE A5.

Age-Standardized Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status and Social Determinants of Health, NHIS, U.S., 2022–2023

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | Type 2 Diabetes* | No Diabetes
Total | 8.7 (0.4) | 8.7 (0.4) | 4.2 (0.1)
Education
Less than high school | 10.4 (1.3) | 10.4 (1.3) | 6.7 (0.5)
High school/GED | 9.8 (0.7) | 9.8 (0.8) | 4.9 (0.2)
More than high school | 7.4 (0.5) | 7.4 (0.5) | 3.5 (0.1)
Poverty income ratio^†^
<1.00 | 13.7 (1.3) | 13.4 (1.4) | 8.6 (0.6)
1.00–2.99 | 9.7 (0.7) | 9.8 (0.7) | 5.4 (0.2)
3.00–4.99 | 7.0 (0.8) | 7.0 (0.8) | 3.6 (0.2)
≥5.00 | 4.9 (0.6) | 4.7 (0.6) | 2.3 (0.2)
Insurance status
Any insurance | 8.8 (0.4) | 8.8 (0.4) | 4.2 (0.1)
Private | 5.9 (0.5) | 5.9 (0.5) | 3.3 (0.2)
Medicare | 12.7 (0.9) | 12.5 (0.9) | 7.8 (0.5)
Medicaid | 15.0 (1.4) | 14.9 (1.4) | 8.7 (0.6)
Urban-rural county-level classification of residence^‡^
Metropolitan
Large central metro | 8.3 (0.8) | 8.0 (0.8) | 3.8 (0.2)
Large fringe metro | 8.0 (0.9) | 8.3 (1.0) | 3.9 (0.2)
Medium and small metro | 9.0 (0.7) | 9.0 (0.7) | 4.5 (0.2)
Nonmetropolitan | 9.8 (0.9) | 9.8 (1.0) | 4.8 (0.3)

All data are self-reported. Data are age-standardized to the NHIS 2022–2023 population with diabetes, using age categories 20–44, 45–64, and ≥65 years. GED, general equivalency diploma; MSA, metropolitan statistical area.

* Type 2 diabetes is defined as self-report of a physician diagnosis of diabetes, excluding participants with probable type 1 diabetes. Probable type 1 diabetes defined as self-report of type 1 diabetes, continuous insulin use within 1 year of diagnosis, and current insulin use.

† The poverty income ratio is defined as total family income divided by the poverty threshold for the family’s size.

‡ Large central metro are counties in MSAs of 1 million or more population that (1.) contain the entire population of the largest principal city of the MSA, (2.) are completely contained in the largest principal city of the MSA, or (3.) contain at least 250,000 residents of any principal city of the MSA. Large fringe metro are counties in MSAs of 1 million or more population that do not qualify as large central. Medium and small metro are counties in MSAs of 250,000 to 999,999 population or in MSAs of less than 250,000 population. Nonmetropolitan are counties in micropolitan statistical areas and non-core counties.

SOURCE: National Health Interview Surveys (NHIS) 2022–2023

APPENDIX TABLE A6.

Prevalence of History of Stroke Among Adults Age ≥20 Years, by Diabetes Status and State or Territory, BRFSS, U.S., 2022–2023

STATE OR TERRITORY OF RESIDENCE | PERCENT (STANDARD ERROR)
STATE OR TERRITORY OF RESIDENCE | Diagnosed Diabetes | No Diabetes
Alabama | 10.2 (1.0) | 6.6 (0.5)
Alaska | 10.5 (1.2) | 4.6 (0.3)
Arizona | 8.9 (0.8) | 4.4 (0.3)
Arkansas | 13.2 (1.1) | 5.8 (0.3)
California | 8.2 (0.8) | 3.8 (0.2)
Colorado | 7.9 (0.9) | 3.4 (0.2)
Connecticut | 9.0 (1.3) | 3.3 (0.3)
Delaware | 8.8 (1.2) | 4.7 (0.4)
District of Columbia | 13.1 (1.7) | 4.7 (0.5)
Florida | 9.9 (0.9) | 4.1 (0.3)
Georgia | 10.1 (0.8) | 4.6 (0.3)
Hawaii | 8.5 (1.0) | 4.1 (0.3)
Idaho | 8.4 (0.9) | 4.2 (0.3)
Illinois | 8.3 (1.1) | 4.4 (0.5)
Indiana | 9.9 (0.6) | 5.2 (0.2)
Iowa | 7.9 (0.7) | 3.8 (0.2)
Kansas | 7.5 (0.6) | 4.2 (0.2)
Kentucky | 12.4 (1.7) | 5.4 (0.6)
Louisiana | 13.0 (1.1) | 6.1 (0.4)
Maine | 12.1 (1.0) | 4.1 (0.2)
Maryland | 8.6 (0.6) | 3.9 (0.2)
Massachusetts | 6.1 (0.7) | 3.7 (0.3)
Michigan | 9.1 (0.7) | 4.4 (0.2)
Minnesota | 9.4 (0.7) | 4.2 (0.2)
Mississippi | 11.6 (1.1) | 6.1 (0.6)
Missouri | 11.5 (1.0) | 5.6 (0.4)
Montana | 8.9 (0.9) | 4.3 (0.3)
Nebraska | 7.3 (0.7) | 3.7 (0.2)
Nevada | 6.8 (1.3) | 4.4 (0.5)
New Hampshire | 8.9 (1.0) | 3.5 (0.2)
New Jersey | 8.5 (1.1) | 3.4 (0.3)
New Mexico | 7.4 (1.2) | 4.6 (0.5)
New York | 7.0 (0.6) | 3.8 (0.2)
North Carolina | 13.2 (1.5) | 5.6 (0.6)
North Dakota | 7.7 (0.9) | 3.8 (0.3)
Ohio | 10.6 (0.6) | 5.1 (0.2)
Oklahoma | 10.6 (0.9) | 5.3 (0.3)
Oregon | 11.9 (1.2) | 4.2 (0.3)
Pennsylvania | 14.4 (3.1) | 4.8 (0.7)
Rhode Island | 8.2 (1.0) | 3.3 (0.3)
South Carolina | 10.6 (0.8) | 4.9 (0.2)
South Dakota | 5.8 (0.9) | 4.4 (0.6)
Tennessee | 13.0 (1.1) | 5.9 (0.4)
Texas | 9.6 (0.9) | 4.8 (0.3)
Utah | 7.6 (0.8) | 3.8 (0.2)
Vermont | 8.1 (1.0) | 3.8 (0.3)
Virginia | 10.9 (0.8) | 4.9 (0.3)
Washington | 7.8 (0.5) | 4.0 (0.2)
West Virginia | 11.8 (0.9) | 6.3 (0.4)
Wisconsin | 10.3 (0.7) | 4.0 (0.2)
Wyoming | 8.6 (1.0) | 4.4 (0.3)
Guam | 12.3 (3.6) | 4.7 (0.9)
Puerto Rico | 4.8 (0.7) | 3.4 (0.4)
Virgin Islands | 12.1 (3.4) | 7.3 (2.4)^1^

All data are self-reported. Diagnosed diabetes is defined as self-report of a diagnosis of diabetes by a physician or other health professional.

^1^ Relative standard error >30%–40%

SOURCE: Behavioral Risk Factor Surveillance System (BRFSS) 2022–2023