# Steering Committee

## Editors

### Jean M. Lawrence, ScD, MPH, MSSA, FACE

Senior Advisor for Diabetes Epidemiology, Division of Diabetes, Endocrinology and Metabolic Diseases, National Institute of Diabetes and Digestive and Kidney Diseases, National Institutes of Health, Bethesda, MD

### Sarah Stark Casagrande, PhD

Senior Epidemiologist, Social & Scientific Systems, Inc. (A DLH Holdings Company), Silver Spring, MD

### William H. Herman, MD, MPH

Stefan S. Fajans/GlaxoSmithKline Professor of Diabetes, Professor of Internal Medicine, Division of Metabolism, Endocrinology, and Diabetes; Professor of Epidemiology, School of Public Health, University of Michigan, Ann Arbor, MI

### Deborah J. Wexler, MD, MSc

Chief, Massachusetts General Hospital Diabetes Unit; Associate Professor, Harvard Medical School, Boston, MA

### William T. Cefalu, MD

Director, Division of Diabetes, Endocrinology and Metabolic Disease, National Institute of Diabetes and Digestive and Kidney Diseases, National Institutes of Health, Bethesda, MD

## Faculty

### Edward J. Boyko, MD, MPH

Professor, Department of Medicine, University of Washington; Veterans Affairs Puget Sound Health Care System, Seattle, WA

### Kai McKeever Bullard, PhD, MPH

Senior Epidemiologist, Division of Diabetes Translation, Centers for Disease Control and Prevention, Atlanta, GA

### Dana Dabelea, MD, PhD

Distinguished Professor and Director, Lifecourse Epidemiology of Adiposity and Diabetes (LEAD) Center Department of Epidemiology; Department of Pediatrics, University of Colorado Anschutz Medical Campus, Aurora, CO

### Sanjoy Dutta, PhD

Chief Scientific Officer, JDRF International (formerly known as Juvenile Diabetes Research Foundation), New York, NY

### Robert H. Eckel, BS, MD

Professor of Medicine, Emeritus, Division of Endocrinology, Metabolism & Diabetes, Division of Cardiology, University of Colorado Anschutz Medical Campus, Aurora, CO

### Hertzel C. Gerstein, MD, MSc

Professor and Population Health Research Institute Chair in Diabetes, McMaster University, Hamilton, Ontario, Canada

### Jennifer B. Green, MD

Professor of Medicine, Division of Endocrinology and Duke Clinical Research Institute, Department of Medicine, Duke University School of Medicine, Durham, NC

### Irl B. Hirsch, MD

Professor of Medicine, University of Washington Diabetes Institute, University of Washington School of Medicine, Seattle, WA

### Marie-France Hivert, MD, MMSc

Associate Professor, Department of Population Medicine, Harvard Medical School and Harvard Pilgrim Health Care Institute, Harvard University, Boston, MA

### Elbert S. Huang, MD, MPH

Professor of Medicine and Public Health Sciences, Section of General Internal Medicine, Department of Medicine, University of Chicago, Chicago, IL

### Robert W. Lash, MD

Chief Medical Officer, Endocrine Society, Washington, DC

### James B. Meigs, MD, MPH

Professor of Medicine, Harvard Medical School, and Physician, Division of General Internal Medicine, Department of Medicine, Massachusetts General Hospital, Boston, MA

### Robert Ratner, MD

Professor of Medicine, Division of Endocrinology and Metabolism, Georgetown University School of Medicine, Washington, DC

### Stephen S. Rich, PhD, FAHA

Harrison Professor, Center for Public Health Genomics, Department of Public Health Sciences, and Department of Biochemistry and Molecular Genetics, University of Virginia, Charlottesville, VA

### Desmond Schatz, MD

Professor of Pediatrics, Medical Director, Diabetes Institute, University of Florida College of Medicine, Gainesville, FL

### Jay S. Skyler, MD, MACP, FRCP

Professor of Medicine, Pediatrics & Psychology, Division of Endocrinology, Diabetes, & Metabolism; Deputy Director - Diabetes Research Institute, University of Miami Miller School of Medicine, Miami, FL

### Miriam Udler, MD, PhD

Assistant Professor, Harvard Medical School, and Physician, Diabetes Unit and Center for Genomic Medicine, Massachusetts General Hospital, Boston, MA

## Project Staff

### Danita D. Byrd-Clark

Senior Project Manager, Social & Scientific Systems, Inc. (A DLH Holdings Company), Silver Spring, MD

### Michelle A. Cissell, PhD

Science Writer/Editor, Dallas, TX

### Patricia Walker

Research Associate/Senior Technical Writer-Editor, Social & Scientific Systems, Inc., Silver Spring, MD