# Risk Factors for Type 1 Diabetes

## Summary

Type 1 diabetes can be diagnosed at any age, but the incidence rate is highest in adolescence, and most available data on risk factors are on children and adolescents. The disease is likely caused by a combination of genetic and environmental factors. This article focuses primarily on environmental risk factors, while the genetics of type 1 diabetes is extensively covered in a separate Diabetes in America article and addressed only briefly herein. The incidence of type 1 diabetes is increasing at an average annual rate of 2%–5%, which suggests a major environmental exposure has changed, by either the gradual introduction of a susceptibility factor or the removal of a protective factor, during the past 60 or more years. Outbreaks and seasonality of type 1 diabetes may suggest an infectious cause, perhaps related to improving sanitation and loss of herd immunity. Early childhood diet and environmental toxins are also of interest.

Prospective studies following high-risk children from birth to development of the subclinical phase of the disease (islet autoimmunity) and diabetes have been the most reliable source of information regarding risk factors for type 1 diabetes. Prenatal and early postnatal exposures appear to be critical, as the incidence of islet autoimmunity peaks in the second year of life. Among infectious agents, enteroviral infections, particularly if they are acquired in infancy and persistent, have gained the most interest. Early leads suggesting a role for cow’s milk exposure in the initiation of islet autoimmunity have not been confirmed by large prospective studies and a large, randomized clinical trial. While numerous prospective studies have reported 1.5–2-fold increases in the risk of islet autoimmunity or type 1 diabetes with various components of early childhood diet and infectious exposures, none of the associations appears particularly strong or consistent across different populations.

Type 1 diabetes is likely caused by the interplay of genetic and environmental factors. Systematic investigation of gene-environment interactions in large, prospectively followed cohorts of young children may help the field identify and fully characterize modifiable risk factors and design trials to evaluate the strongest candidate triggers of autoimmunity.

## Introduction

Since the publication of Risk Factors for Type 1 Diabetes in Diabetes in America, 3rd edition (1), the literature base has grown significantly on the incidence of type 1 diabetes and associated risk factors, including genetic, infectious, nutritional, toxins, psychosocial and socioeconomic, prenatal, and environmental. Type 1 diabetes can be diagnosed at any age (2,3,4), but the incidence rate is highest in adolescence, and most available data on risk factors come from children and adolescents. The incidence of type 1 diabetes has increased worldwide since the 1950s (5). The rate of increase has varied between regions and over time, with an average of about 2%–5% annual increase in incidence rate among children in most continents during the 1990s (6) and also more recently, although the incidence has tended to plateau in some countries after around 2005 (Figure 1) (6,7,8,9,10,11,12,13,14,15,16,17,18,19,20,21,22,23,24,25,26). Annual percent changes of 2%–5% in the incidence correspond to doubling of incidence rates approximately every 15–40 years. Individuals of non-European ancestry have been observed to have lower absolute incidence rates in some countries, such as the United States (8) and Sweden (10). However, the trends in groups with non-European ancestry appear similar to those in the populations overall, although typically with a higher annual percent increase in populations of non-European ancestry that increase from a lower absolute rate (8,10). The rate of change in incidence cannot be explained by changes in the frequency of genetic susceptibility variants in the population and must be attributed to yet-unknown environmental factors. The rising incidence, outbreaks (27), and a seasonal pattern (28) may suggest that infectious agents play a role in the pathogenesis of type 1 diabetes, but such a secular trend is unlikely to result from a new infectious agent. However, similar to the polio model (29), an “old” microbe could express its diabetogenic effect due to increasing hygiene and decreasing herd immunity. Prospective studies following high-risk children from birth have made important inroads into understanding the role of infectious and dietary factors in type 1 diabetes.

### Screening for Presymptomatic Disease and Stages of Disease

Prospective studies have defined two major stages in the pathogenesis of type 1 diabetes (30). Seroconversion to positivity for islet autoantibodies (to insulin, glutamic acid decarboxylase [GAD], insulinoma antigen 2 [IA-2], or zinc transporter 8 [ZnT8]) marks the development of islet autoimmunity, and the presence of two or more type 1 diabetes-associated islet autoantibodies and normoglycemia define Stage 1 of the disease. Stage 2 is defined as the additional presence of dysglycemia and is presymptomatic. The risk of progression to clinical type 1 diabetes (Stage 3) is particularly high for children who develop two or more islet autoantibodies. Approximately 50% of such children develop type 1 diabetes in the first 5–6 years (31,32), while the 10-year risk was 70% and the 20-year risk was over 90% in one study with such long follow-up (31). In contrast, most children persistently positive for only one islet autoantibody do not progress to diabetes during childhood; the 10-year risk of progression was 14.5% in the joint analysis of the study mentioned above (31). Children with a single autoantibody may also experience resolution of autoimmunity (33).

Evidence suggests that a variety of exposures may trigger islet autoimmunity, promote progression from islet autoimmunity to clinical diabetes, or affect both of these steps (Figure 2A). To disentangle the potential influences of islet autoimmunity initiation versus progression, costly study designs with frequently collected serial blood samples from birth or early life are necessary. In practice, the actual time of seroconversion is not observed, and ensuring that timing of exposures, such as infections, occurred before onset of islet autoimmunity is difficult, as illustrated in Figure 2B (34).

When assessing potential risk factors for developing islet autoimmunity, exposures such as infections in the period before seroconversion to islet autoimmunity (exemplified by child 1 and child 2 in Figure 2B) must be compared with the corresponding period for children who did not develop islet autoimmunity in the corresponding time window (exemplified by child 3 in Figure 2B, vertical arrow 1). When investigating factors potentially influencing risk of progression from islet autoimmunity to clinical type 1 diabetes, exposures must be studied in the period after seroconversion but before clinical type 1 diabetes, as illustrated with vertical arrow 2 in Figure 2B. Some studies have compared exposures, such as infections, in individuals with existing islet autoimmunity to controls without islet autoantibodies, as illustrated with vertical arrow 3 in Figure 2B comparing Child 2 to Child 3. This approach could lead to reverse causation bias, which is exposure influenced at least in part by the disease process rather than vice versa. For example, if the disease process associated with islet autoimmunity were to lead to a general increase in titers of existing antibodies to viruses or make individuals more susceptible to infections, biased associations may be observed even in prospective studies unless this potential bias is considered in the selection of samples and during statistical analysis.

Studies of risk factors for islet autoimmunity have started to incorporate analyses of distinct subtypes, usually defined by the type of the first-appearing islet autoantibody. For instance, insulin autoantibodies tend to be associated with the human leukocyte antigen (HLA) DQ8 haplotype and to appear earlier than anti-GAD and other islet autoantibodies (35,36,37). According to the concept of endotypes of type 1 diabetes, different subtypes may be caused or influenced by different combinations of risk factors and may even have distinct functional pathobiological mechanisms (38,39,40). While it is difficult in practice to decide for any individual patient whether his or her disease resulted from a specific pathobiological mechanism, the study of observable phenotypes, such as first-appearing islet autoantibodies, may represent a way of embracing this concept and explain some of the inconsistencies in the literature. Studying subtypes of disease comes at a cost of smaller sample sizes and higher number of comparisons with typically lower statistical power for each study.

Most existing prospective data concerning risk factors for islet autoimmunity and type 1 diabetes come from a handful of prospective studies that have sometimes generated inconsistent results. Some inconsistencies may be due to differences in study design and research methods, but perhaps some are due to differences in the disease process among individuals, as discussed above. While harmonized analyses replicating findings across several large prospective birth cohorts may reconcile some inconsistencies, randomized clinical trials of risk factor modifications will provide the ultimate test. Because of the time, cost, and other resources required to carry out well-powered randomized prevention trials, it is important that they build on the best available pre-trial evidence. Ethics and other practical aspects also make some etiological research questions difficult or impossible to test in scientifically well-designed trials.

This article focuses on environmental risk factors; however, type 1 diabetes is widely believed to be caused by a combination of many different genetic and environmental factors. Pertinent aspects of the genetics of type 1 diabetes are briefly summarized in the next section. In the remainder, evidence for environmental risk factors for type 1 diabetes, including gene-environment interactions, is reviewed.

## Genetic Factors

### Family History of Type 1 Diabetes

In the United States, the population cumulative incidence (probability) of developing type 1 diabetes is approximately 1:300 to 1:250 (0.33% to 0.40%), with some variation depending on time period, geographic location, and ethnic group (7,41,42,43). For comparison with older estimates in affected relatives, the 1:300 estimate for the general population is used in Table 1. The risk is increased to about 1:40 (2.5%) in offspring of mothers with type 1 diabetes and 1:15 (6%–7%) in offspring of fathers affected by type 1 diabetes; this difference may have an epigenetic origin. The risk to siblings of individuals with type 1 diabetes ranges from 1:35 to 1:12 (3% to 8%) (44,45). The risk is significantly higher in siblings of individuals diagnosed at age <7 years than in siblings of individuals who were diagnosed later (46). Risk is as high as 1:3 to 1:2 (33% to 50%) among monozygotic twins, if they are followed for several years (47,48). In parents of individuals with type 1 diabetes, the risk by age 40 years is 2.6% and twofold higher in fathers (3.6%) than in mothers (1.7%) (46). By age 60 years, an estimated 10% of first-degree relatives will develop type 1 diabetes (49). However, the “familial” cases account for less than 10% of type 1 diabetes in the general population; they do not differ from “sporadic” cases in terms of HLA-DR-DQ gene frequencies or the prevalence of islet autoantibodies (50).

Similar to type 1 diabetes, the risk of developing islet autoimmunity varies depending on which relative has type 1 diabetes (Table 1). Siblings of individuals with type 1 diabetes develop islet autoimmunity more frequently than their offspring or parents (51). The risk of islet autoimmunity is markedly increased if both parents or a parent and a sibling have type 1 diabetes compared with having a single affected family member (52). In The Environmental Determinants of Diabetes in the Young (TEDDY) study (a longitudinal birth cohort of children from the United States, Sweden, Germany, and Finland), having an affected first-degree family member with type 1 diabetes was not significantly associated with risk of progression from islet autoimmunity to clinical type 1 diabetes but was clearly associated with increased risk of islet autoimmunity, with some differences between type of affected relative and which autoantibody appeared first (Figure 3) (37).

### Candidate Genes

The molecular genetics of type 1 diabetes is reviewed in the Diabetes in America article Genetics of Type 1 Diabetes (53). The increased risk seen in family members can be attributed to both shared genes and shared environment. The strongest genetic association for type 1 diabetes is with certain alleles of the HLA class II genes (odds ratio [OR] >6). Population-based association studies have shown that the odds ratio of type 1 diabetes when comparing those with the highest risk HLA-DR4-DQ8/DR3-DQ2 genotype to those with at least one dominantly protective HLA-DQ6 haplotype is approximately 200 (54). An estimated 30%–40% of the familial aggregation or variance in liability for type 1 diabetes is attributable to the HLA region (55,56). At least 78 confirmed non-HLA genomic regions confer susceptibility to type 1 diabetes, each with modest to small effects (57,58). Non-HLA loci most strongly associated with type 1 diabetes include INS (59) and PTPN22 (60), each with an odds ratio of approximately 2. One reason why these genes seem to have relatively small effects is that they may need to work in concert with another factor, such as an environmental exposure, as covered in the Gene-Environment Interactions section.

The non-HLA gene variants studied more thoroughly so far appear to be important to both the triggering of islet autoimmunity and the progression to clinical disease; however, few studies are sufficiently powered to tease out this distinction. In TEDDY, among participants carrying high-risk HLA genotypes, established type 1 diabetes non-HLA susceptibility variants on the ImmunoChip contributed to risk of developing islet autoimmunity (e.g., single nucleotide polymorphisms [SNPs] near INS, PTPN22, SH2B3, ERBB3) (61). Genetic risk scores including both HLA and non-HLA SNPs tended to contribute to progression from islet autoimmunity to clinical type 1 diabetes but were less predictive of progression than of the development of islet autoimmunity (62). The established HLA-DR-DQ genotypes that are most strongly associated with type 1 diabetes mentioned above predict islet autoimmunity but typically not progression from two or more islet autoantibodies to clinical type 1 diabetes (37,63,64).

SNPs associated with susceptibility for type 1 diabetes are involved in aspects of immunity, and some of those are also involved in antiviral defense (58). A 2022 analysis of TEDDY data showed that in addition to family history of type 1 diabetes and HLA susceptibility genotypes, non-HLA SNPs in or near INS, PTPN22, SH2B3, ERBB3, and other genes were associated with risk of persistent positivity for at least one islet autoantibody but not with progression from multiple islet autoimmunity to clinical type 1 diabetes (Figure 3) (37).

Consistent with TEDDY, an analysis of the Finnish Diabetes Prediction and Prevention Study (DIPP) cohort reported that SNPs in or near INS, PTPN22, and ERBB3 predicted islet autoimmunity and that the INS SNP did so only for those who developed insulin autoantibodies first (65). Because the DIPP paper only reported progression from the first islet autoantibody and not from seroconversion for two or more islet autoantibodies to clinical type 1 diabetes (65), the DIPP progression results cannot be compared to those from TEDDY (37). Finally, some studies have suggested that HLA class I alleles to some degree predict progression from multiple islet autoantibodies but in a complex fashion depending on other loci and antibody profile (66). Statistical power to detect genetic associations in cohort studies of islet autoimmunity and progression remains limited, even in the largest of such studies.

### Genetic Risk Scores

Polygenic risk scores (calculated as a sum of risk alleles across SNPs confirmed to be associated with type 1 diabetes susceptibility and weighted by the logarithm of the allelic odds ratio) contribute to prediction of islet autoimmunity and type 1 diabetes (67,68). On the one hand, a simple two-SNP genetic screening can provide useful prediction of type 1 diabetes for many purposes (69). With the availability of a large number of SNPs associated with type 1 diabetes (57,58), obtaining more accurate predictions should be possible (67,68,70); however, many technical issues arise in calling of SNPs from genome-wide genotyping platforms, selection of SNPs to include, and weighting of allele scores. The use of external information for weighting allele scores is essential to avoid overfitting and, thus, overly optimistic predictions. Furthermore, most scores have been developed from data in European-origin populations. While ancestry-specific scores are emerging and showing somewhat better predictive utility for type 1 diabetes, the area under the receiver operating characteristic curve (AUC) for such scores in non-European-origin populations is within 0.75–0.85 in most studies (68). In (European-origin) population-based studies, a simple four-level categorization of HLA-DQ-DR genotypes gives an AUC of around 0.8, while the addition of a non-HLA genetic risk score marginally increases the AUC (54,70,71).

TEDDY, TrialNet, and other studies recruiting first-degree relatives and/or children with HLA susceptibility genotypes have an initial screening step. This restriction to high-risk individuals leads to a sample of participants with less variation and increased concentration of higher genetic risk scores compared to the general population. The AUCs for genetic risk scores in such studies are expected to be lower than those in population-based studies of similarly constructed genetic risk scores. Still, TEDDY found that genetic risk scores within the genetically susceptible population can aid in further prediction of islet autoimmunity and progression to type 1 diabetes (62,72). While an AUC of 0.8 in general is considered a relatively good prediction, the low a priori (population) risk of type 1 diabetes in the general population means that the absolute risk among those with high-risk scores may still be limited. When a higher cutoff for a genetic risk score is used, the absolute risk in the included group becomes higher. At the same time, the high-risk (“screen-positive”) group becomes a smaller proportion of the population when the cutoff is set high. For instance, TEDDY included around 10% of HLA-screened individuals for follow-up. The 25% of the TEDDY participants with the highest genetic risk score had an estimated 11% absolute risk of developing multiple islet autoantibodies (72). This group of high-risk individuals therefore represents a proportion of the general population that would be approximately 25% of 10%, which is 2.5%. In the Norwegian Environmental Triggers of Type 1 Diabetes (MIDIA) study following the approximately 2.2% of general population newborns with the HLA-DR4-DQ8/DR3-DQ2 genotype, 8% developed type 1 diabetes by age 15 years ((73) and L. C. Stene, unpublished data).

### Increasing Penetrance of the Moderate-Risk HLA Genotypes

Several studies have explored temporal changes in the frequency and/or distribution of HLA genotypes associated with type 1 diabetes susceptibility (Table 2) (74,75,76,77,78,79,80). All but one have suggested a decreasing frequency of the highest-risk HLA-DR-DQ genotype over time in individuals diagnosed with type 1 diabetes.

A study conducted in Finland reported a significant decrease in the frequency of the HLA-DRB1*03-DQB1*0201/DRB1*04-DQB1*0302 genotype from 25.3% to 18.2% over a 62-year time period (76). A similar decrease in the frequency of the highest-risk HLA genotypes (from 47% to 35% over a 50-year time period) was noted in the United Kingdom (80). A study combining Type 1 Diabetes Genetics Consortium participants and a Colorado clinic population cohort (74) showed a similar linear decrease. Additional evidence for decreasing frequency of the highest-risk genotype was published from Colorado (75), Sweden (78), and Australia (77). The study from Colorado was the only one with data on ethnic groups, and the authors reported similar trends for Hispanic and non-Hispanic White patients (75). The decrease in the frequency of cases with the highest-risk HLA genotype with the corresponding increase in moderate and lower risk genotypes suggests an increasing penetrance of moderate and lower risk HLA genotypes that could be explained by increasing environmental pressure, e.g., higher levels of exposure to the critical factor.

## Infections

Prospective studies of high-risk children have shown that the incidence of islet autoimmunity peaks in the second year of life (35,81,82), suggesting that the putative environmental trigger(s) must occur very early in life in many cases. Therefore, in utero, perinatal, or early childhood infections and infant diet are likely candidate exposures.

### Seasonality

Type 1 diabetes incidence in children is higher in autumn-winter and lower in spring-summer in both hemispheres, resembling the seasonality of viral infections (83,84,85). In some studies, children age 11–15 years show more obvious seasonal variation compared to children diagnosed before age 5 years (86), which may suggest that additional factors play a role, e.g., easier detection of the onset of diabetes signs/symptoms in children attending school. Enterovirus infection may occur near clinical onset (87). Development of islet autoimmunity could also depend on an environmental exposure during pregnancy, as suggested by seasonality of islet autoantibodies in cord blood (88). A seasonal distribution of birth dates of type 1 diabetes patients has been reported in some studies, although most large studies have not found any major association between season of birth and risk of type 1 diabetes (89,90,91,92).

### Frequency of Infectious Disease Symptoms

Most episodes of childhood infections are never diagnosed, and the etiological agent is never identified. It seems that the most frequent infections are viral and affect the respiratory system (93). In a setting where no or only mild symptoms are associated with most infections with enterovirus and probably also other pathogens (94), it may be relevant to study symptomatic infections. Symptomatic infections are more likely to be associated with inflammatory responses and high levels of cytokines systemically and in infected tissues (95).

Early observations linked the onset of type 1 diabetes to antecedent viral illnesses, but these illnesses probably precipitated symptoms and diagnosis in many cases. Given the long prodromal period in the development of type 1 diabetes, prospective studies of infections before islet autoimmunity or months or years before type 1 diabetes are necessary to make it plausible that infections causally influence the risk of disease.

While early studies by Gamble suggested that antecedent respiratory infections and illness were not associated with type 1 diabetes (96,97) and the field traditionally has focused on gut infections, evidence is accumulating that frequent symptomatic respiratory infection is associated with at least a slight increase in risk of islet autoimmunity and/or type 1 diabetes. The Norwegian MIDIA study was the first to report an association between respiratory tract infections and increased risk of islet autoimmunity (i.e., parent-reported higher frequency of lower respiratory tract infections was associated with a threefold increased risk of islet autoimmunity) (98). Similar findings were subsequently reported from the BABYDIET birth cohort from Germany (99) and in the TEDDY study (100). Respiratory infections in a German claims database were also associated with increased risk of type 1 diabetes (101), while respiratory infections prospectively reported in the child’s first 18 months of life in around 80,000 general population children in the Norwegian Mother, Father and Child Cohort study (MoBa) were not associated with type 1 diabetes (102). However, hospitalizations for gastroenteritis, although rare, tended to be associated with increased risk of type 1 diabetes in MoBa (102). Similarly, the Diabetes Autoimmunity Study in the Young (DAISY) in Colorado found an association between islet autoimmunity and early childhood gastrointestinal infections, but not respiratory infections (103). Finally, infections in early life, routinely recorded by family doctors, were not associated with subsequent childhood type 1 diabetes in a U.K. population-based study of 367 cases and 4,579 matched controls (104).

In summary, several studies support a potential nonspecific association with frequency of symptomatic infections. Inconsistencies are likely because infectious disease is complex with respect to timing and interindividual differences in immune responses. Only limited attempts have so far been made to identify the pathogens behind respiratory infections in relation to islet autoimmunity or type 1 diabetes (105), but the large number of different pathogens will make it difficult to study specific pathogens with sufficient statistical power in prospective studies.

### Viral Infections

Viral infections have long been implicated in the etiology of type 1 diabetes, and several potential mechanisms for this link have been proposed (106,107,108); however, definitive proof has been elusive. Footprints of infectious triggers of islet autoimmunity may be hard to detect due to a long incubation period of type 1 diabetes in most cases. Several agents have been suggested to trigger autoimmune diabetes. Enterovirus has been studied since the 1960s, and most recently, severe acute respiratory syndrome coronavirus 2 (SARS-CoV-2) and viruses identified in viromics sequencing studies have been investigated.

The outcome of infection may differ in individuals with islet autoimmunity compared to those with unaffected islets. The outcome is also likely modulated by complex interactions between the microbe and the host. Viruses present at diagnosis may have infected the host late in the disease process rather than trigger the process. Alternatively, a triggering infection has likely been cleared by the time of diagnosis, unless the virus is able to persist. Viral infections may potentially initiate islet autoimmunity, modulate progression to clinical type 1 diabetes (87,109,110,111,112), or both (Figure 2).

As stated, enterovirus has been the most frequently studied viral infection. Enteroviruses have shown associations with type 1 diabetes in both animal and human studies. Formally, the genus Enterovirus (of family Picornaviridae) encompasses several species, including Enterovirus A–D as well as Rhinovirus A–C, and each species includes many types. Currently, the International Committee on Taxonomy of Viruses (ICTV (113)) recognizes 25 types of Enterovirus A, including coxsackieviruses A2–8 and enterovirus 71, and at least 64 types of Enterovirus B, including coxsackieviruses B1–6 and coxsackievirus A9. Species Enterovirus C encompasses 27 virus types, including polioviruses 1–3. Most focus in the type 1 diabetes field has been on coxsackie B viruses, but many human studies using molecular methods of virus detection have not been able to determine the exact type of enterovirus. When speaking of enteroviruses, non-polio members of Enterovirus A–D are referred to herein, unless otherwise specified.

Enteroviruses are nonenveloped and have a positive sense, single-stranded RNA genome of around 7.5 kilobases (114). Most infections are asymptomatic or associated with mild symptoms but can occasionally cause moderate to severe conditions, including gastroenteritis, pancreatitis, respiratory infections, meningitis, and paralysis (115). Enteroviruses are believed to primarily replicate in the gut or respiratory tract, with most types being detectable in fecal samples and some being detectable in respiratory samples, either primarily (e.g., coxsackievirus D68) or occasionally (e.g., coxsackieviruses B1 and B4) (115). At least some enteroviruses have tropism to human pancreatic islets in vivo and in vitro (116,117,118). Signs of enterovirus genomes or protein have been detected in the pancreata of type 1 diabetes patients and in donors with islet autoimmunity in small amounts but more frequently than in controls (119,120,121,122). Animal studies suggest that the timing of an infection may be critical (109,111,112).

### Enteroviral Infections

#### Retrospective Studies of Enterovirus Serology

The initial observation of an association between enteroviral infections and type 1 diabetes made by Gamble in 1969 was based on apparently higher prevalence of antibodies against coxsackievirus in patients with recently diagnosed type 1 diabetes than in controls (97). A systematic review by Green et al. of serologic case-control studies up to 2002 concluded that results were heterogeneous between studies and that differences between studies in design and serologic assay made it difficult to draw firm conclusions (123). Green et al. specifically reviewed coxsackieviruses B3, B4, and B5, and none showed clear overall evidence for association. In a more recent multinational case-control study of recent-onset type 1 diabetes, Oikarinen et al. tested serum-neutralizing antibodies towards the six coxsackie B viruses (124). In that study, coxsackievirus B1 was more common in cases than controls, with a significant odds ratio of 1.7 (95% confidence interval [CI] 1.06–2.74), while coxsackieviruses B2–6 showed no significant difference between cases and controls (124).

#### Retrospective Studies of Enterovirus RNA in Blood

Studies detecting enterovirus genomic RNA using reverse transcription-polymerase chain reaction (RT-PCR) in serum, plasma, or whole blood among newly diagnosed type 1 diabetes patients and matched controls across 12 studies published from 1995 to 2011 showed a consistent tenfold more frequent enterovirus detection in patients with type 1 diabetes compared to controls (reviewed in detail (1,125)). However, while the studies varied little in the frequency of enterovirus RNA in healthy controls, wide variation was seen in the frequency of enterovirus RNA in newly diagnosed type 1 diabetes patients, where the earliest studies showed a higher frequency of infection among patients than did the more recent ones. Improvements over time in the sensitivity of enterovirus detection may explain some of the heterogeneity, but notably, one laboratory that previously detected enterovirus in numerous samples found no enterovirus RNA in any sample from type 1 diabetes patients at diagnosis in three independent data sets (87,126,127).

Several studies have indicated that detection of enterovirus RNA with RT-PCR is more likely in peripheral blood mononuclear cells (PBMCs) than in plasma or serum (128,129,130). A report of young adults with type 1 diabetes and controls detected enterovirus RNA in PBMCs from 9 of 37 individuals with type 1 diabetes (24.3%) compared with 10 of 35 individuals without type 1 diabetes (28.6%), showing no significant difference (130).

#### Prospective Studies of Enterovirus and Risk of Islet Autoimmunity

Prospective studies can exclude the possibility that the virus detected in patients infected them after disease onset. Such studies can also demonstrate causation if a virus triggers autoimmunity through a “hit and run” mechanism. Challenges include sampling frequency to capture infectious agents while they are present in biological specimens and statistical power, if the infection is rare or very common. While researchers have hypothesized that enterovirus may be linked to type 1 diabetes via persistence, no direct evidence for this theory has been found (106). Enterovirus overall is very common and essentially infects all children before age 2 years. However, studies with monthly collection of stool samples rarely find enterovirus by PCR in more than two or three consecutive samples (125). The TEDDY study showed associations between repeated presence of Enterovirus B in longitudinal stool samples and risk of islet autoimmunity (Figure 3) (131), as discussed in the next section.

The longitudinal studies investigating enteroviral infections as potential triggers of islet autoimmunity varied in sample frequency, method of virus detection, and sample size (Table 3). While most early publications from longitudinal birth cohort studies included few cases with islet autoimmunity and, thus, limited statistical power, more recent analyses from the Finnish DIPP and the international TEDDY birth cohort studies with longitudinal analysis of genetically susceptible children have included larger sample sizes. Below, results of prospective studies of enterovirus and islet autoimmunity or type 1 diabetes are summarized separately for different types of samples used for virus detection (Table 4).

##### Virus Detection in Stool Samples

Three early publications from cohort studies of newborns with genetic susceptibility for type 1 diabetes followed longitudinally (DIPP from Finland, MIDIA from Norway, and BABYDIET from Germany) reported separate results from stool samples; none showed any significant association with islet autoimmunity (132,133,134). DIPP found a tendency towards an association, but the result was only significant when combined with enterovirus serology (132). A larger update from DIPP reported an association between early enterovirus shedding and islet autoimmunity months to years later (135). In this study of several thousand fecal samples, with sequencing of VP1 (viral envelope protein 1) in positive samples, coxsackievirus B1 was not detected, and coxsackievirus B4 was detected in four case samples and zero control samples (135). At least for coxsackievirus B1, this rarity may be due to its more frequent detection in respiratory samples than in fecal samples in surveillance studies (136). However, coxsackievirus B1 was detected more often in controls in TEDDY than was coxsackievirus B4 (see below), although most enterovirus types are less frequent in Finland compared to the other TEDDY centers (131).

In the Australian Viruses in the Genetically at Risk (VIGR) study, no association was found between frequency of enterovirus RNA in 32 fecal samples from cases with islet autoimmunity and 32 matched control samples (137). Subdividing by enterovirus species, Enterovirus A (7/32 in cases vs. 2/32 in controls) and Enterovirus B (4/32 in cases vs. 3/32 in controls) tended to be more common in cases with islet autoimmunity than in controls (137), but neither difference was statistically significant. The authors also reported that despite the lack of significant difference in enterovirus frequency, the abundance of Enterovirus A was higher in cases than controls along with a remarkably large number of other viruses that showed differential abundance (137). Using the same approach, coxsackievirus B4 was less abundant in islet autoimmunity cases than in controls (137). Some bioinformatics and biostatistical methods used for such differential abundance testing are, however, susceptible to false discoveries (138,139). Both standardization and validation of the analysis pipelines and replication are therefore necessary before strong conclusions can be drawn regarding differential abundance of fecal viromes (131).

TEDDY, with monthly longitudinal sampling, has been the largest study to date. Among 383 matched sets of islet autoimmunity cases (one or more of three islet autoantibodies) and controls in TEDDY, common types of viruses detected in feces by sequencing were tested for association (131). Fecal shedding of the same type of Enterovirus B in at least two consecutive samples showed a particularly strong association with islet autoimmunity (OR 3.05, 95% CI 1.64–5.69) (131). No significant interactions between fecal Enterovirus B shedding and HLA susceptibility genotypes were found, meaning that the odds ratio for association was similar across HLA types in TEDDY. In subgroup analyses of specific Enterovirus B types (regardless of duration of positivity), only coxsackievirus B4 was nominally significant (131). However, in contrast to the analysis of islet autoimmunity case-control sets, in the 93 case-control sets with type 1 diabetes as the outcome, no significant difference was observed for Enterovirus A–D overall, but positivity for any of the Enterovirus B types tended to be inversely associated with type 1 diabetes (OR 0.73, 95% CI 0.53–0.99) (131). Additional results from the TEDDY virome study are reported in the Other Viruses section.

##### Viral Biomarkers in Blood

Early publications from the Finnish birth cohorts DIPP and the Trial to Reduce IDDM in the Genetically at Risk (TRIGR) reported significant associations with islet autoimmunity when combining enterovirus RNA in serum with infections defined serologically based on serial increase in at least one of several assays. The fact that the large majority of infections were detected with serology suggests that serology was driving this association (140,141). In another DIPP report, no significant association was found between serologically defined infections in serial samples from age 3–24 months and later risk of islet autoimmunity in 107 children with islet autoimmunity and 446 matched controls (142). BABYDIAB analyzed enterovirus serology (143), but infrequent sampling and, in many instances, only one or no sample available from before islet autoimmunity limited the power to detect any relationship. In an early analysis of DAISY, a longitudinal birth cohort of genetically susceptible children in Colorado, no significant serologic association was found between enterovirus and islet autoimmunity ((144) and M. Rewers, unpublished observation). The largest prospective analysis of enterovirus serology to date included 183 cases of multiple islet autoimmunity and matched controls in the Finnish DIPP study (145). In this study, neutralizing antibodies to 41 different enterovirus serotypes were measured in serial samples at birth (cord blood), at 6 and 12 months before seroconversion for islet autoantibodies, and in the first islet autoantibody-positive sample from each child, where available. Observed odds ratios for association with islet autoimmunity varied from 0.4 to 1.5, with 3 of 41 serotypes showing nominal significance (i.e., significant without correction for multiple testing). Coxsackievirus B1 was positive in 59% of cases and 50% of controls, translating to a nominally borderline, significantly increased risk of islet autoimmunity (OR 1.5, 95% CI 1.0–2.2), while coxsackieviruses B3 and B6 were associated with lower risk of islet autoimmunity (OR 0.4, 95% CI 0.2–0.8 and OR 0.6, 95% CI 0.4–1.0, respectively, the latter being nominally of borderline statistical significance) (145). Coxsackievirus B4 tended to be more common in controls than in those with islet autoimmunity, but this result was not significant (145). Similar findings were reported in a multinational case-control study reviewed above, with the potential caveat that samples were collected after diagnosis of type 1 diabetes (124).

The Norwegian MIDIA study tested for enterovirus genomic RNA in the cell fraction of serial blood samples from 45 cases who subsequently developed multiple persistent islet autoimmunity and matched controls and found no significant association between the presence of enterovirus in blood before the seroconversion interval and risk of islet autoimmunity (146). In the first islet autoantibody-positive sample, enterovirus positivity tended to be more common, but this finding was not significant, with a very wide 95% confidence interval (OR 8.7, 95% CI 0.97–77.0) (146). Another noteworthy observation in MIDIA was that although not significant, enterovirus RNA positivity in blood was more common after seroconversion in cases compared to age-matched intervals in autoantibody-negative controls. This result may have been due to reverse causation, i.e., susceptibility to infection being higher in those with islet autoimmunity.

A report including 39 children with islet autoimmunity from DIPP found enterovirus more frequently in PBMCs from islet autoimmunity cases than in islet autoantibody-negative control children (130). Enterovirus RNA was detected in PBMCs in 14 of 49 children with multiple islet autoantibodies with or without progression to type 1 diabetes (28.6%) compared with 1 of 30 matched control children without autoantibodies or type 1 diabetes (3.3%, OR 11.6, 95% CI 1.9–127) (130). However, no information was provided about the number of samples and timing of those samples with regard to time of seroconversion or diagnosis of type 1 diabetes in each subject, making interpretation difficult.

#### Prospective Studies of Enterovirus in Progression From Islet Autoimmunity to Type 1 Diabetes

Two studies from Finland—Childhood Diabetes in Finland (DiMe) and DIPP—found that positive enterovirus RNA and serology tests preceded development of type 1 diabetes (126,127,147). The hypothesis that enterovirus infections can promote progression from islet autoimmunity to type 1 diabetes is consistent with animal model data (109,148). Among children with islet autoimmunity, DAISY was the first to report a higher rate of progression to type 1 diabetes in sample intervals after detection of enterovirus RNA in serum (87). Remarkably, none of the samples available from the day of type 1 diabetes diagnosis were positive for enterovirus RNA. This finding suggests that the observed association was not due to reverse causality. A report of 39 cases of islet autoimmunity in DIPP reported no significant difference in the frequency of enterovirus in PBMCs from such children who did progress to clinical type 1 diabetes versus those who did not. However, the lack of information about the number and timing of samples analyzed, as noted in the previous section, makes it difficult to interpret these results with regard to progression (130). Finally, while TEDDY did not formally analyze the fecal virome in relation to progression, the tendency towards an inverse association with Enterovirus B and clinical type 1 diabetes suggests that this group of viruses did not play a major role in progression (131).

#### Prenatal Enterovirus Infection and Development of Type 1 Diabetes

Some studies have suggested a relationship between prenatal infections and risk of type 1 diabetes in childhood (147,149,150,151), while a number of others have not found any significant relationship (141,143,152,153). There are many methodologic differences between these studies, including the timing of exposure assessment (the first trimester, third trimester, or birth). In a larger study sample from DIPP with 171 mothers of children who developed type 1 diabetes and controls matched for HLA type and other factors, serological evidence for enterovirus infection during pregnancy was documented in 19% of cases and 12% of controls, corresponding to a significant association with odds ratios of 1.7 to 2.2, depending on the definition of infection (154). In the enterovirus serology investigation in DIPP, seropositivity in cord blood tended to be associated with a lower risk of islet autoimmunity or at least attenuation of the positive association with coxsackievirus B1 (145).

### SARS-CoV-2

By December 2022, many small studies had reported inconsistent results regarding changes in the incidence and seasonality of new-onset type 1 diabetes during the coronavirus disease of 2019 (COVID-19) pandemic compared to the period before. For instance, studies from Germany, Norway, Czech Republic, and the United States reported a slight increase in 2020 and 2021 compared to prepandemic periods (Figure 1) (19,155,156). Because the increase was seen in periods where the population cumulative incidence of infection with severe acute respiratory syndrome coronavirus 2 (SARS-CoV-2) in children was documented to be relatively low (on the order of 2%–10%), any changes in type 1 diabetes incidence were most likely due to indirect effects of the pandemic rather than direct effects of infection. Anecdotal evidence from case-reports of new-onset diabetes after SARS-CoV-2 infection combined with in vitro evidence that this virus may infect the pancreas, and possibly islets and beta cells, spurred interest in the question of whether SARS-CoV-2 can increase the risk of type 1 diabetes. Although it seems clear that SARS-CoV-2 may infect the pancreas, many details remain controversial and in vitro findings are sensitive to experimental conditions, as highlighted elsewhere (157,158). Based on the limited duration of the SARS-CoV-2 pandemic at the time of this report, a potential effect on rate of progression from preexisting islet autoimmunity to clinical type 1 diabetes is probably more plausible than initiation of islet autoimmunity, if anything.

A systematic review of the bidirectional associations of COVID-19 and diabetes published in December 2022 identified 14 publications on new-onset diabetes of any type among children and/or adults (159), only two of which included children and/or young adults with possible type 1 diabetes and one study of diabetes (any type) among <18-year-olds (160). By the end of December 2022, we identified four additional prospective registry-based studies (summarized in Table 5), as well as a study of islet autoimmunity, as discussed below. Some studies lacked detailed description of their methods and data, and several studies had methodological shortcomings.

The first published study based on U.S. claims databases included all types of diabetes before age 18 years and suggested an association (160), but the analysis likely included some prevalent cases of type 1 diabetes because the observed incidence of diabetes was much higher than that reported from other studies in the United States (8). Subsequent studies also used commercial claims databases without proper description of methods, including different publications using the same database; several of these studies suggested associations between SARS-CoV-2 and risk of type 1 diabetes with relative risks (RR) around 1.5 in at least some age-groups (Table 5) (161,162,163). Whole population registries with good quality and similar methodology showed no association in Scotland (164) and Denmark (165), but a significantly increased risk in Norway (166). Finally, SARS-CoV-2 antibodies were not associated with islet autoimmunity in screening studies of over 50,000 youths in diverse populations of Colorado and Bavaria (167). In this latter study, islet autoimmunity may have developed before SARS-CoV-2 infection. Longer follow-up will help assess whether SARS-CoV-2 infection may affect the risk of islet autoimmunity or accelerate progression from preexisting autoimmunity to clinical diabetes.

### Other Viruses

A large number of viruses have been associated with type 1 diabetes in case reports or other small studies, but most are unconfirmed. Many older studies that have not been replicated were described elsewhere (1). Here, we review some other viruses that have been studied for potential association with islet autoimmunity or type 1 diabetes, primarily from prospective studies, concluding with a review of studies that have used viromics sequencing.

The genera Parechovirus and Cardiovirus of the Picornaviridae family have shown no association with islet autoimmunity or type 1 diabetes in serial fecal samples from MIDIA, DIPP, or TEDDY (131,168,169,170). Influenza A serology showed no association with islet autoimmunity in DIPP (Finland) (171), but severe symptomatic infections with influenza A H1N1 during the 2009–2010 pandemic in Norway were associated with increased risk of type 1 diabetes in a population-based registry study (172).

Rotavirus infects beta cells (173) and may have a link to islet autoimmunity by way of molecular mimicry (174); however, evidence for a causal role is lacking (175). A longitudinal Australian study reported an increased incidence of islet autoantibodies shortly after detection of rotavirus infection (176). A Finnish study that measured rotavirus antibodies in serum samples collected at 3- to 6-month intervals up to age 2 years did not confirm the association (177). See results related to rotavirus vaccinations in the Vaccines section.

Cytomegalovirus (CMV) has been implicated in the etiology of type 1 diabetes, primarily using serological evidence (178,179,180). In contrast, several epidemiologic studies have failed to demonstrate a link between CMV and the development of islet autoantibodies or type 1 diabetes (181,182,183). A first analysis in the Finnish DIPP study suggested no association between positivity for CMV IgG antibodies in early life and risk of islet autoimmunity or progression from autoimmunity to type 1 diabetes in young children with type 1 diabetes risk-associated HLA genotypes (184). A later DIPP analysis confirmed the lack of association with islet autoimmunity but reported a lower rate of progression in children with early signs of CMV infection (185).

High-throughput (“next-generation”) sequencing technologies are being applied to human studies of viruses in causation of type 1 diabetes (186,187). With larger and higher quality data sets, such as those from TEDDY (131,188), more sophisticated statistical analyses can be used to separate information from noise. Progress in sequencing technologies has offered attractive new possibilities to detect microbes in biological samples and carry out metagenomic studies where the whole microbiome and virome can be explored in the context of islet autoimmunity and type 1 diabetes (189,190,191). This approach concerns not only previously known microorganisms, but also novel ones. Despite the availability of machine learning algorithms, the richness of exposure information represents a risk of false positives, and replication in independent cohorts is essential to ensure the reproducibility of findings. Among all common viruses detected in the fecal virome in TEDDY, only human Adenovirus C was significant after correction for multiple testing and was associated with a lower risk of islet autoimmunity (Figure 4) and type 1 diabetes (131). In a 2021 systematic review of the few and generally small virome studies of type 1 diabetes or islet autoimmunity (except the large TEDDY study), enterovirus again seemed most promising (187), as reviewed in the Enteroviral Infections section.

### The Hygiene Hypothesis and the Polio Model of Type 1 Diabetes

The hygiene hypothesis was originally formulated based on the observation that atopic eczema occurred more frequently in firstborn children compared to those with older siblings (who typically are exposed to more infections), but the hypothesis has since expanded to encompass autoimmune diseases and has become a complex theory with potentially many different mechanisms at play (192). Several more specific hypotheses have been proposed, which may be viewed as variants of the hygiene hypothesis or hygiene theory, including missing helminths (193), missing biodiversity (194,195), and the polio model reviewed in the next subsection. As discussed, the frequency of childhood infections tends to be associated more often with higher rather than lower risk of islet autoimmunity or type 1 diabetes. Missing microbes in this context include not only infections, but also missing exposure to microbial products, such as lipopolysaccharide and other compounds that may stimulate the immune system. Modern practices, such as vaccination and the use of antimicrobials, are also held responsible for the increasing occurrence of immune-mediated diseases according to this theory. The hygiene hypothesis, or hygiene theory at large, is difficult to reject, but we examine in turn different types of exposures, typically indicators of microbial exposure. Household crowding, day care attendance, and exposure to animals may capture exposure that is difficult to measure directly; these factors may provide leads towards potential etiologic agents, but such proxies are typically confounded with other factors, such as ethnicity and socioeconomic status, that are often not accounted for in studies.

Birth order has shown inconsistent associations with type 1 diabetes, and a pooled analysis of more than 30 studies showed an overall slightly lower risk of type 1 diabetes in second or later born children compared to first born (OR 0.90, 95% CI 0.83–0.98) (196).

Infectious agents typically spread more easily in densely populated areas; however, results of studies of population density or urbanicity in relation to risk of type 1 diabetes have been inconsistent (197). Incidence of type 1 diabetes tends to be lower in large cities and densely populated areas compared to less densely populated rural areas in the Nordic countries (198,199,200). The interpretation of these studies is complex because most have not accounted for typical differences in ethnic composition and that larger and typically densely populated cities within most countries tend to have more people who are foreign-born than rural areas in the same countries. In other words, associations between population density and incidence of type 1 diabetes are likely to have been at least partially confounded by ethnicity and nativity status.

Household crowding (number of persons per room in the residence when the child was age 6 months) was not significantly associated with islet autoimmunity in DAISY (201). In a registry-based cohort from Turin, Italy, individual-level household crowding was defined by the number of persons per area of the residence and analyzed in three equally sized groups. In this study, results were only shown stratified in three age groups, 0–3, 4–14 and 15–29 years (the interaction between age and crowding was significant, p_(interaction)_=0.006). Crowding was associated with a borderline significantly higher risk of type 1 diabetes in the 0–3-year-olds (high vs. low crowding; RR 2.91, 95% CI 0.99–8.56), and there was no significant association in the 4–14-year-olds, whereas crowding tended to be associated with a (nonsignificant) lower risk of type 1 diabetes at age 15–29 years (high vs. low crowding; RR 0.76, 95% CI 0.47–1.21) (202).

Living in a farm environment has been associated with a more diverse microbiota and lower risk of asthma (203); however, studies of islet autoimmunity or type 1 diabetes have not suggested any such association. In a questionnaire-based comparison of 242 prevalent cases with type 1 diabetes and hospital-based controls in Germany, no significant association between living on a farm or regular contact with farm animals and risk of type 1 diabetes was found (204). In the Finnish DIPP cohort, family occupation in farming (OR 1.58, 95% CI 0.36–6.96) or child contact with farm animals in the first year of life (OR 0.79, 95% CI 0.12–5.15) was not significantly associated with risk of type 1 diabetes (205). In a large registry-based cohort of over one million children from Norway, having parents working with farming was not associated with risk of type 1 diabetes in children (206).

Exposure to animals, including pets such as cats and dogs, was tested in an analysis of several early life indicators of microbial exposure in the Finnish DIPP cohort. Only indoor dog exposure was associated with lower risk of islet autoimmunity (OR 0.47, 95% CI 0.28–0.80) and similarly, but nonsignificantly, for type 1 diabetes (OR 0.40, 95% CI 0.14–1.14), whereas exposure to cats was not associated with islet autoimmunity or type 1 diabetes (205). In the DAISY cohort in Colorado, having cats or dogs in early life was not associated with islet autoimmunity (201).

Helminths, especially Enterobius vermicularis (pinworm), were proposed by Gale as a missing factor possibly responsible for the increasing incidence of type 1 diabetes (193). However, no association between prescriptions of anti-worm medication and risk of type 1 diabetes was observed in a registry-based study from Denmark, where medication against pinworm is sold mainly at pharmacies (207). Among the few more recent studies screening for infestation with pinworm, the MIDIA study showed that pinworm is still very common and often asymptomatic, at least in Norwegian children (208).

Use of antibiotics in childhood has consistently been shown in large cohort studies not to be associated with risk of islet autoimmunity or type 1 diabetes (102,205,209,210,211,212,213). Maternal use of antibiotics during pregnancy has also not been associated with type 1 diabetes in children in large cohorts (102,210,214).

The polio model of type 1 diabetes is an analogy between the epidemiology of poliomyelitis and that of type 1 diabetes described by Gamble in 1980 (215). As noted, polioviruses are enteroviruses. Prior to 1880, most infants were infected with poliovirus during the first year of life (29). These infections were generally mild due to the presence of maternal anti-poliovirus antibodies transmitted transplacentally or in breast milk (216). Viremia was limited, and infection of the central nervous system and paralysis were rare. Importantly, infants acquired active immunity under the cover of passive protection from maternal antibodies, with waning protection during the first year of life. Improved hygiene led to a delay of the initial infections, some until the second year of life, past the period when infants are usually protected by maternal antibodies (29). The median age at poliovirus infection increased gradually with associated morbidity until widespread vaccination became available. Notably, a very low proportion of those infected with poliovirus developed poliomyelitis, or acute flaccid paralysis—around 1 in 150 or less (29). Researchers have hypothesized that in countries with the highest incidence of type 1 diabetes, increased hygiene and sanitation resulted in a decline in frequency and titer of antibodies to enteroviruses among pregnant women and, hence, fewer maternally transferred antibodies, exposing fetuses and newborns to prenatal or infant enteroviral infections (217). Virus-induced diabetes can be prevented in animal models of offspring by infecting mothers with the same virus prior to pregnancy (218), but direct evidence supporting the polio model for type 1 diabetes in humans is still lacking.

In summary, the best available evidence from human observational studies does not support the hygiene hypothesis for type 1 diabetes, including exposure to vaccines (see the next section). Testing whether specific interventions can be effective may be possible, but early attempts in this direction have not yet been powered to study islet autoimmunity or type 1 diabetes (195).

### Vaccines

As childhood immunization programs have expanded, there has been speculation that vaccines may play a role in the development of childhood diseases that have risen in incidence, such as type 1 diabetes (219). Fortunately, no association between immunizations and islet autoimmunity or type 1 diabetes has been found thus far (219,220,221,222). In 2016, a meta-analysis reviewed 23 studies investigating 16 vaccinations and analyzed 11 studies that met the inclusion criteria (223). Overall, no evidence was found to suggest an association between any of the childhood vaccinations investigated and type 1 diabetes. The pooled odds ratios ranged from 0.58 (95% CI 0.24–1.40) for the measles, mumps, and rubella (MMR) vaccination in five studies up to 1.04 (95% CI 0.94–1.14) for the Haemophilus influenzae serotype B (HiB) vaccination in 11 studies. Significant heterogeneity was present in most of the pooled analyses but was markedly reduced when analyses were restricted to study reports with high methodology quality scores. A comprehensive study using the Vaccine Safety Datalink confirmed the lack of association between childhood vaccinations in the United States and risk of type 1 diabetes (224). Also, detailed analysis of vaccination records in two birth cohorts of German children with genetic susceptibility for type 1 diabetes (BABYDIAB/BABYDIET) found no association between vaccinations and risk of islet autoimmunity in genetically susceptible children (225).

The Bacillus Calmette-Guérin (BCG) vaccine has attracted some interest as a potential immunomodulator that could theoretically reduce the incidence of autoimmune diabetes; however, human data for any association between BCG vaccination and type 1 diabetes or islet autoimmunity are universally negative. Until 2006, BCG was routinely administered to all neonates in Finland, the country with the highest incidence of type 1 diabetes in the world (12,13,226). Although the incidence of type 1 diabetes has stopped rising since 2006 (Figure 1), it is difficult to link the two events causally. Studies from Canada (227) and Sweden (228) have shown no association of BCG vaccination with the risk of type 1 diabetes. The German BABYDIAB study reported no association with development of islet autoimmunity or type 1 diabetes, although that study suggested a faster progression in autoantibody-positive children who were vaccinated before age 3 years (229). A 20-year follow-up of the 1974 Canadian birth cohort, of which 45% were given BCG in the first year of life, also showed no association (230). In addition, vaccination with BCG at diagnosis of type 1 diabetes does not increase the remission rate or preserve beta cell function (231,232).

Work is ongoing to test whether enterovirus vaccination may reduce the risk of islet autoimmunity or type 1 diabetes, and caution is necessary to ensure that such vaccines do not have any side effects. Live attenuated enterovirus vaccination was not associated with islet autoimmunity in children predisposed to type 1 diabetes in Finland (233).

Oral rotavirus vaccination has been introduced in the routine childhood vaccination program of many countries since 2006. A possible lower incidence of type 1 diabetes was seen in vaccinated cohorts in United States (234) and Australia (235), whereas no significant association was seen in Finland (236). Follow-up of participants in a randomized trial of Rotateq in Finland did not find any difference in the incidence of type 1 diabetes after 12–14 years (237). No association (hazard ratio [HR] 1.03) was reported in the Vaccine Safety Datalink in the United States (238) nor in a large study from England (239). In their review, Burke et al. (240) concluded that the evidence suggests a possible relationship between some wild-type rotavirus infections and type 1 diabetes, but the effect of rotavirus vaccination for the prevention of type 1 diabetes remains inconclusive.

The Pandemrix vaccine (with the squalene-containing adjuvant system 03, AS03) against the influenza A H1N1 strain, which caused the 2009–2010 flu pandemic, was not associated with type 1 diabetes in a population-wide study in Norway (241) nor in the multinational TEDDY study of genetically susceptible children (242).

Finally, while several case-reports of individuals developing diabetes after SARS-CoV-2 vaccinations have been published, this outcome is inevitable in a setting where billions of vaccine doses have been administered over a few months globally. A study in Scotland investigated SARS-CoV-2 vaccines in relation to subsequent risk of type 1 diabetes and found no association (164). SARS-CoV-2 vaccination was not associated with subsequent risk of type 1 diabetes in a similar analysis from Norway (243).

### Intestinal Microbiota

In addition to viruses, bacterial infections and commensal microbiota may modulate the risk of type 1 diabetes (244). The mucosal immune system has specialized regulatory mechanisms to tolerate commensal microorganisms. Some candidate environmental factors that appear to affect the risk of type 1 diabetes (e.g., cesarean section delivery, early childhood diet, use of antibiotics) are intertwined with the development and function of the human microbiome. Evidence is growing that the “Western” diet has altered the genetic composition and metabolic activity of the gut microbiota. Emerging data support the hypothesis that altered gut bacterial composition may play a role in development of type 1 diabetes (189,190,245,246,247,248,249,250), as reviewed by Siljander et al. (251). Some studies have reported lower microbial diversity in children with islet autoimmunity before progression to diabetes compared to healthy controls (189,190,244,245,250).

TEDDY examined fluctuations in the microbiota from at-risk children over time starting at age 3 months and found that the majority of variability in the metagenomes was explained by age, geographical location, and breastfeeding of the subjects (189,190). Analyses of the TEDDY islet autoimmunity cases and controls indicated a greater presence of Lactobacillus rhamnosus and Bifidobacterium dentium in controls, while islet autoimmunity cases had a higher abundance of Streptococcus species (189). Similarly, analyses of type 1 diabetes cases and controls indicated that controls had higher abundance of lactic acid-producing bacteria, while the type 1 diabetes cases had a higher abundance of Bifidobacterium pseudocatenulatum, Roseburia hominis, and Alistipes shahii (189). The aforementioned associations were borderline nonsignificant after correction for multiple testing (false discovery rate corrected q-values 0.055–0.11). Moreover, pathways involved in the synthesis of short chain fatty acids (SCFA) were enriched in control subjects (189). Intriguingly, TEDDY found that early exposure (age <28 days) to probiotics from supplements and formula in infancy was associated with a decreased risk of islet autoimmunity (252), suggesting that the mechanism behind this association might be through impact of probiotics on the child’s microbiome (Table 6; see also the Gene-Environment Interactions section). An ongoing randomized primary prevention trial expected to end in 2024 is testing whether early supplementation with Bifidobacterium longum subspecies infantis can reduce the risk of islet autoimmunity in genetically susceptible children (253).

Except for TEDDY, most previous studies have been small, and many have included patients with prevalent disease and, thus, have been susceptible to potential reverse causation. Sample handling and bioinformatics pipelines can influence results. Considering the vastly complex and multifaceted microbiome, more standardization and replication of results from large-scale studies are necessary before robust conclusions can be drawn, especially regarding causality.

## Nutritional Factors

Dietary factors associated with the appearance of islet autoimmunity and progression from islet autoimmunity to type 1 diabetes are reviewed in this section. Table 6 summarizes these findings, with reference to studies showing associations with islet autoimmunity, progression, or risk of type 1 diabetes separately (see also the Gene-Environment Interactions section and Table 7).

### Maternal Nutritional Exposures During Pregnancy

Here, we review selected nutrients and dietary constituents, while subsequent sections cover other relevant factors, such as maternal obesity in the Prenatal and Perinatal Factors section and circulating metabolites in the Metabolomics Studies section.

Vitamin D exposure during the intrauterine period may be of special importance for the development of the fetus (254). The seasonality of birth in children with type 1 diabetes and/or the presence of a seasonal pattern at diagnosis of type 1 diabetes could be explained by seasonal variation in endogenous vitamin D production via exposure to the sun (255,256). In a meta-analysis, the pooled odds ratio with maternal intake of vitamin D during pregnancy was 0.95 (95% CI 0.66–1.36), suggesting no effect of vitamin D intake (257). A Norwegian study found an association between higher serum 25-hydroxy vitamin D (25(OH)D) in samples collected in late pregnancy and lower risk of type 1 diabetes in the offspring (258), whereas a Finnish study found no such association with samples collected in the first trimester of pregnancy (259). Subsequent large studies found no association between 25(OH)D levels in pregnancy (260) or at birth (260,261,262) and risk of type 1 diabetes in the offspring. Vitamin D in the postnatal period is reviewed in a subsequent section.

Higher dietary gluten intake during pregnancy was associated with higher risk of type 1 diabetes in the Danish National Birth Cohort (DNBC) (263), but this finding was not confirmed in the similarly designed Norwegian MoBa study (264). In the international, multicenter TEDDY study, neither maternal gluten intake nor any other food intake during pregnancy was associated with the development of islet autoimmunity (265). Childhood gluten intake is reviewed in the Solid Foods, Cereals, and Gluten section.

Data regarding maternal intake of micronutrients (from foods and supplements) are inconsistent. In the Norwegian MoBa study, maternal use of iron supplements during pregnancy was associated with a higher risk of type 1 diabetes in the offspring (adjusted HR 1.33, 95% CI 1.06–1.67) (266), although iron supplement use was not associated with islet autoimmunity or type 1 diabetes in at-risk children in Finland (DIPP) (267). Similarly, development of islet autoimmunity in the offspring was not associated with maternal intake of antioxidants from foods and supplements in DIPP (267,268) nor with omega-3 fatty acid supplement use in pregnancy in TEDDY (269). Similarly, in Norway, a prospective study of docosahexaenoic acid (DHA), eicosapentaenoic acid (EPA), and other fatty acids in the phospholipid fraction of maternal serum collected in late pregnancy found no association with risk of type 1 diabetes before age 15 years (270).

### Breastfeeding

Breastfeeding has several potentially beneficial effects but is notoriously difficult to study due to potential recall bias and confounding because it is associated with so many other factors. Many older studies were summarized in a pooled analysis of 43 retrospective studies, which showed a small reduction in the risk of type 1 diabetes associated with exclusive breastfeeding for >3 months (OR 0.87, 95% CI 0.75–1.00) and any (i.e., nonexclusive) breastfeeding for >3 months (OR 0.88, 95% CI 0.78–1.00) (271).

All but one of the prospective cohort studies failed to find an association between breastfeeding duration and islet autoimmunity (221,272,273,274,275,276,277,278,279,280,281,282). While a Norwegian study (MIDIA) found that breastfeeding for 12 months or more was associated with a lower risk of progressing from islet autoimmunity to type 1 diabetes (280), the Finnish DIPP study found no association between breastfeeding duration and progression to type 1 diabetes (279). Never being breastfed, but not shorter exclusive or partial breastfeeding duration, was associated with increased risk of type 1 diabetes in the Norwegian and Danish birth cohorts (283), which has important implications with regard to infant feeding and public health guidelines.

Breastfeeding may be viewed as a surrogate for a delay in the introduction of diabetogenic substances, such as cow’s milk that is present in formula or solid foods, such as cereals. DAISY found evidence that a child who is still breastfeeding at the time of introduction to cereals has a reduced risk of islet autoimmunity (273), and a subsequent analysis in DAISY showed that breastfeeding at the time of introduction to gluten-containing grains, specifically, conferred protection for the development of type 1 diabetes (HR 0.47, 95% CI 0.26–0.86) (274). These findings suggest that while not strongly protective independently, breastfeeding may be a protective factor in the relationship among other dietary factors, such as cow’s milk or cereals (as further described in the following sections).

### Cow’s Milk

Cow’s milk introduced at weaning triggers insulitis and diabetes in animal models (284,285). Older case-control studies of humans were susceptible to recall and selection biases and also showed inconsistent results. Most prospective cohort studies have not shown any significant association between age at introduction of cow’s milk and either islet autoimmunity (273,275,276,277,278,286) or type 1 diabetes (274).

A large, multinational, double-blind, randomized trial (TRIGR), in which infants at genetically increased risk for type 1 diabetes were assigned to receive either a casein hydrolysate formula or a conventional, cow’s milk-based formula (control) whenever breast milk was not available during the first 6–8 months of life found no effect of the intervention on development of islet autoimmunity (287). Analysis of the primary outcome, type 1 diabetes, also showed no effect (288). Interestingly, the use of hydrolyzed infant formula compared with cow’s milk-based formula was found to increase the risk of islet autoimmunity in the large observational cohort study TEDDY (289).

Studies exploring whether the amount of childhood cow’s milk consumption may be associated with the risk for islet autoimmunity and type 1 diabetes have also produced contradictory results. Cow’s milk intake in childhood has been associated with both an increased risk of islet autoimmunity (290,291) and type 1 diabetes (292), as well as a decreased risk of type 1 diabetes (293). In the Finnish DIPP cohort, cow’s milk intake during childhood was weakly associated with increased islet autoimmunity risk (290). While a similar analysis in the DAISY cohort found no association between cow’s milk intake and islet autoimmunity risk, increased cow’s milk intake was associated with progression to type 1 diabetes in children with islet autoimmunity (HR 1.59, 95% CI 1.13–2.25) (294).

In an analysis of DIPP, increased serum levels of pentadecanoic-, palmitic-, and palmitoleic acids were associated with an increased risk of islet autoimmunity (295). Because these serum fatty acids are biomarkers of milk and ruminant meat fat (296,297), this observation suggests that higher current consumption of milk and meat may be associated with risk of islet autoimmunity. The inconsistencies across these studies may be due to the modifying effects of the underlying genetic profile. This possibility is further described in the Gene-Environment Interactions section.

### Solid Foods, Cereals, and Gluten

In addition to breast milk substitutes, such as infant formulas, the infant is exposed to other dietary antigens in the first year of life that may impact oral tolerance or the immune system. Prospective studies of children at increased risk for type 1 diabetes from both Germany (BABYDIAB) and Colorado (DAISY) have shown an increased risk for islet autoimmunity associated with first exposure to cereals prior to the third month of life when compared with introduction in the fourth to sixth months of life. In DAISY, the timing of introduction of any type of cereal (gluten and non-gluten-containing) was associated with an increased islet autoimmunity risk, and the study also found a U-shaped relationship between risk and age at introduction—the nadir of the curve occurring with introduction in the fourth to sixth months of life (273). In contrast, BABYDIAB showed an association with gluten specifically and found that a further protective effect was conferred if foods containing gluten were introduced after the sixth month (276). Given the difference in the defined dietary variables (the non-gluten-containing food variable in BABYDIAB contained non-cereal foods), it is difficult to determine whether the two studies contradict each other regarding whether the driving antigen was gluten. The Finnish DIPP study suggested that introducing gluten-containing cereals between ages 5 and 5.5 months was associated with an increased risk of islet autoimmunity compared with introducing gluten after age 5.5 months, although this association was only significant when follow-up was restricted to the first 3 years of life (278). No increased risk of islet autoimmunity was associated with introducing gluten earlier than age 5 months compared with after age 5.5 months. In the TEDDY prospective cohort, later introduction of gluten in infancy was associated with increased risk of islet autoimmunity (HR 1.05, 95% CI 1.01–1.10 for every 1-month delay) (281).

Intervention studies in islet autoantibody-positive children indicate that while a gluten-free diet may not decrease autoantibody titers (298,299), it may improve beta cell function (299). However, an intervention study, in which 150 high-risk infants were randomly assigned to a first gluten exposure at age 6 months (control group) or 12 months (late-exposure group), found that delaying gluten exposure until age 12 months did not substantially reduce the risk for islet autoimmunity in genetically at-risk children, nor did it increase the risk (300,301).

Other solid foods in the infant diet besides gluten and cereals have been implicated in the etiology of islet autoimmunity. In the Finnish DIPP study, introduction of root vegetables by age 4 months was associated with an almost twofold increased risk for islet autoimmunity compared with introducing root vegetables after age 4 months (278). DIPP also found that first exposure to egg before age 8 months was associated with an increased risk of islet autoimmunity compared with introducing egg after age 11 months, but this association was only significant when the analysis was restricted to the first 3 years of life (278). These cross-study differences may be related to country differences in the first solid food that is typically introduced to infants. In the United States, cereals, particularly rice cereal, are often the first solid foods to be introduced to the infant (273), whereas in other countries, root vegetables and fruits are more common first solid foods, suggesting that the focus on cereals may not be relevant across countries and may explain these inconsistent results.

DAISY and BABYDIAB have prospectively examined the relation of some of these dietary exposures to clinical type 1 diabetes. In DAISY (274), both early (age <4 months) and late (age ≥6 months) first exposure to any solid food (compared with exposure at age 4–5 months) predicted development of type 1 diabetes (HR 1.91, 95% CI 1.04–3.51 and HR 3.02, 95% CI 1.26–7.24, respectively). Specifically, early exposure to fruit and late exposure to rice/oat predicted type 1 diabetes (HR 2.23, 95% CI 1.14–4.39 and HR 2.88, 95% CI 1.36–6.11, respectively). BABYDIAB (302) reported that exposure to gluten-containing foods before age 3 months, which occurred rarely, increased the risk of developing islet autoantibodies and type 1 diabetes (n=3) compared to exclusive breastfeeding (HR 3.45, 95% CI 1.04–11.48) or compared to first exposure to gluten between ages 3.1 and 6.0 months. In contrast to DAISY, children who received gluten-containing foods after age 6 months did not have an increased risk of islet autoantibodies, multiple islet autoantibodies, or type 1 diabetes.

Several studies have examined the role of the amount of gluten or fiber intake in infancy and early childhood, rather than age at first exposure. Higher intake of gluten in early childhood predicted type 1 diabetes in Norway’s MoBa study (264), and similarly, higher gluten and fiber intake in childhood were associated with increased risk of both islet autoimmunity and type 1 diabetes in the Finnish DIPP (303), but not in Colorado DAISY study participants (304).

In summary, timing and context at introduction of solid foods, such as gluten, as well as the amount of gluten eaten during early childhood, may be associated with risk of islet autoimmunity or type 1 diabetes, but inconsistencies between studies are difficult to reconcile.

### Vitamin D

Vitamin D has been examined as a potentially protective factor because it plays an active role in the regulation of the immune system, as well as in metabolic pathways relevant to diabetes. Prenatal and newborn vitamin D exposure is covered in the Maternal Nutritional Exposures During Pregnancy section.

Multiple studies have examined the role of vitamin D exposure in infancy and childhood in the pathogenesis of type 1 diabetes. In a large historical prospective study from Finland, infants who received no vitamin D supplementation had higher risk of type 1 diabetes than those who did receive supplements (305). Two meta-analyses of retrospective studies showed that the risk of type 1 diabetes was significantly reduced in infants who were supplemented with vitamin D compared to those who were not supplemented (pooled odds ratio 0.71) (257,306). However, many of the included studies were case-control studies with a high risk for selection bias and recall bias.

Determinants of 25(OH)D, the inactive circulating form of vitamin D and an established marker of vitamin D status, include sun exposure, dietary intake (supplements, fatty fish, and vitamin D-fortified dairy foods), and genetic predisposition. The aforementioned studies were limited in that they were only able to examine dietary intake of vitamin D and were not able to examine vitamin D exposure via sun exposure. The first two large prospective studies (DAISY and DIPP) to examine serial plasma or serum 25(OH)D levels in childhood reported no association with development of islet autoimmunity or progression from islet autoimmunity to type 1 diabetes in children at increased risk for diabetes (307,308). However, subsequent studies in at-risk populations have shown that higher 25(OH)D is associated with a small decrease in islet autoimmunity risk in TEDDY (OR 0.93, CI 0.89–0.97 for each 5 nmol/L increase) (309) and TRIGR (OR 0.98, 95% CI 0.97–0.99 for each 1 nmol/L increase) with a similar association for type 1 diabetes (310). Interestingly, in two related nested case-control studies among U.S. active-duty military personnel, those with higher 25(OH)D levels in blood samples collected prior to diabetes diagnosis had a significantly lower risk of developing insulin-requiring diabetes than those with lower 25(OH)D levels (311,312), suggesting a protective effect of vitamin D levels in adult-onset type 1 diabetes cases. While misclassification of type 1 and type 2 diabetes is common in young adults, results were similar in all study participants and those confirmed to have islet autoantibodies. Two clinical trials reported no effect of 1,25-dihydroxyvitamin D3 (calcitriol) supplementation on sustained insulin production among persons with new-onset type 1 diabetes (313,314).

Vitamin D is known to be influenced in part by genetics, particularly by variants located within or near genes involved in vitamin D transport (DBP), cholesterol synthesis (DHCR7), and hydroxylation (CYP2R1 and CYP24A1) (315). Variants near CYP27B1, DHCR7, and CYP2R1 are associated with type 1 diabetes (316). DAISY found that variants in DHCR7 and CYP27B1 were associated with development of islet autoimmunity but not progression to type 1 diabetes in children with islet autoimmunity (317). The DHCR7 variant was also found to be associated with 25(OH)D levels in DAISY children; however, since 25(OH)D levels were not associated with islet autoimmunity or type 1 diabetes risk (307), the effect of this variant is not likely mediated through 25(OH)D levels, suggesting that this enzyme may influence diabetes risk via other mechanisms. While a frequently cited, large-scale Mendelian randomization study reported lower 25(OH)D to be causally associated with increased risk of multiple sclerosis (318), a similar analysis reported that 25(OH)D was unlikely to have a large effect on type 1 diabetes risk (319). These inconsistent findings suggest that the mechanism by which vitamin D may exert its effect on type 1 diabetes is likely to be complex.

### Other Vitamins

Vitamin E, or α-tocopherol, may protect against diabetes in animal models (320,321). While serum α-tocopherol was inversely associated with type 1 diabetes in a small case-control study nested within a 21-year follow-up of adult Finnish men (322), serum α-tocopherol concentrations were not significantly associated with the risk of islet autoimmunity in DIPP (323).

Higher plasma ascorbic acid (vitamin C) in TEDDY children was associated with a lower risk of developing islet autoimmunity (OR 0.96, CI 0.92–0.99 per 1 mg/L) (324). Type 1 diabetes was analyzed in a smaller sample size of 102 cases and 282 controls where the observed odds ratio of association was slightly stronger, but not significant (OR 0.93, 95% CI 0.86–1.02) (324).

### Polyunsaturated Fatty Acids

A relative deficiency of omega-3 fatty acids (also referred to as n-3 fatty acids), a characteristic of many Western diets, may predispose to heightened inflammatory reactions (325). Alpha-linolenic acid (ALA) is the principal omega-3 fatty acid in Western diets and is found in the green leaves of plants and in flax, canola, walnuts, and soy. The next most common omega-3 fatty acids are EPA and DHA, which are found in fatty fish. Fatty acid levels in plasma or serum and fatty acid content of erythrocyte membranes are short-term and long-term markers of fatty acid status, respectively, while the fatty acid composition of the phospholipid fraction of serum or plasma reflects intermediate-term dietary intake.

DAISY reported that higher omega-3 fatty acid intake during childhood was associated with a lower risk of islet autoimmunity and, likewise, that higher omega-3 fatty acid levels in the erythrocyte membrane were associated with a lower risk of islet autoimmunity (326). Subsequent analysis of DAISY indicated that the inverse association between erythrocyte membrane omega-3 fatty acid levels and islet autoimmunity risk was driven by lower docosapentaenoic acid (DPA) levels (327). Similarly, TEDDY found that higher DPA and EPA levels in erythrocyte membranes were associated with decreased risk of islet autoimmunity (328). And while DIPP found that lower serum DHA and a higher arachidonic acid (ARA):DHA ratio were associated with an increased risk of islet autoimmunity (295), no association between serum omega-3 fatty acid levels and risk of islet autoimmunity was observed in TRIGR (329).

### Zinc

Among the many biological functions of zinc, this trace metal plays important roles in synthesis, storage, and secretion of insulin. Autoantibodies to ZnT8 are present in 60%–80% of newly diagnosed patients with type 1 diabetes (330). While different coding variants in the SLC308A locus affect the type of ZnT8 autoantibodies a subject with type 1 diabetes has (331) and are associated with risk of type 2 diabetes (332), genetic variation in this locus is not associated with risk of type 1 diabetes (333). Serum, plasma, or intracellular zinc levels are significantly lower in type 1 diabetes patients than in controls (334,335). However, the role of zinc deficiency in triggering of islet autoimmunity or promoting progression of islet autoimmunity to clinical type 1 diabetes is unclear. Case-control studies of tap water samples suggest lower zinc concentrations in case families (336,337); however, drinking water contributes a small proportion of total ingested zinc. No association between maternal intake of zinc during pregnancy and islet autoimmunity was seen in the DIPP study (268), and newborn blood zinc was not associated with childhood type 1 diabetes in a large Danish study (338). Zinc intake or status, therefore, does not seem to be a risk factor for type 1 diabetes based on current evidence.

### Glycemic Index and Intake of Dietary Sugars

Dietary factors such as glycemic index and glycemic load increase insulin demand and may also stress the beta cells. While development of islet autoimmunity was not associated with glycemic load or glycemic index, progression to type 1 diabetes in children with islet autoimmunity was associated with higher glycemic index and load at the first islet autoimmunity-positive visit in DAISY (339). A subsequent analysis of DAISY with longer follow-up showed that progression from islet autoimmunity to type 1 diabetes was associated with higher total sugar intake and greater consumption of sugar-sweetened beverages (adjusted for total energy intake, but not weight), although the latter association was observed only in children with the high-risk HLA-DR genotype (Table 7) (340). Beta cell stress may promote the generation of neoautoantigens resulting from posttranslational modification of beta cell proteins, which may drive autoimmunity and progression to type 1 diabetes (341).

### Weight, Growth, and Obesity

Higher birth weight has been quite consistently associated with higher risk of type 1 diabetes in large-scale population-based studies, but the magnitude of the association is too weak to play a role in individual risk prediction (342,343,344,345). The finding does, however, hint towards the importance of intrauterine factors.

Several studies indicate that rapid weight gain during the first 1–2 years of life is a risk factor for type 1 diabetes (346,347,348), as systematically reviewed by Harder et al. (345). DAISY, the high-risk cohort in Colorado, showed that neither weight gain in the first 9 months nor in the first 24 months of life was associated with risk of type 1 diabetes (274). However, in the Australian BABYDIAB cohort, higher weight and body mass index (BMI) z-scores at age 6 months were associated with higher risk of islet autoimmunity, as was weight gain at age 2 years (349). Also, greater infant weight gain was significantly associated with increased risk of type 1 diabetes in the large, population-based Norwegian MoBa cohort and the Danish DNBC cohort (HR 1.24 per standard deviation increase in weight gain at age 12 months) (350). A similar magnitude of association was found between infant weight gain and islet autoimmunity in TEDDY, albeit not in the subgroup of children with islet autoimmunity who were diagnosed with type 1 diabetes during follow-up (351).

Increased height growth at age 0–18 months and height from ages 6 to 18 months were higher in cases with type 1 diabetes compared with controls in the Swedish Diabetes Prediction in Skåne (DiPiS) study (352). In DAISY, low early body height but a higher height growth velocity in childhood predicted a higher risk of islet autoimmunity, and height growth velocity also predicted higher progression from islet autoimmunity to type 1 diabetes (353). In TEDDY participants, the rate of height growth in infancy was positively associated with risk of progression from islet autoimmunity to type 1 diabetes, whereas the height growth in early childhood was inversely associated with risk of progression from islet autoimmunity to type 1 diabetes (354).

Obesity and puberty are associated with increased insulin resistance (355). Consistent with the sex-specific peak incidence of type 1 diabetes occurring close to that for onset of puberty, puberty may accelerate the onset of type 1 diabetes via insulin resistance (356,357). However, data linking insulin resistance to islet autoimmunity, progression, or type 1 diabetes are not entirely consistent with this notion as seen, for instance, in the TrialNet Pathway to Prevention study (358). Participants in the German high-risk BABYDIAB cohort who were positive for islet autoantibodies did not have increased insulin resistance (assessed by Homeostatic Model Assessment) compared with age-matched islet autoantibody-negative children at age 8 or 11 years (359). Contrary to the accelerator hypothesis, islet autoimmunity status was associated with decreased insulin resistance values, controlling for age and sex. The accelerator hypothesis proposes that excess weight gain leading to increases in insulin resistance in early childhood initiates the autoimmunity leading to beta cell destruction and type 1 diabetes development (360), for which there is little or no direct evidence. Several studies have shown an association between higher BMI z-scores and earlier age at diagnosis of type 1 diabetes (360); however, this type of study does not constitute a test of the accelerator hypothesis and not even a direct test of the association between childhood BMI and subsequent risk of type 1 diabetes.

Prospective cohorts have tested the relation between childhood BMI and risk of type 1 diabetes. Analysis of the 1970 British Birth Cohort suggested that increased BMI in childhood increased the risk of self-reported type 1 diabetes (361). In an observational analysis of the TRIGR study, overweight or obesity at age 2–10 years was associated with increased risk of islet autoimmunity and type 1 diabetes (362). Furthermore, the Copenhagen growth register linked to diabetes registries showed that BMI z-score at ages 7 and 13 years was associated with an increased risk of type 1 diabetes (OR 1.23 for each standard deviation increase) (363). Finally, in a study of Israeli conscripts age 16–19 years, increased BMI was associated with increased risk of adult-onset type 1 diabetes (HR 1.54, 95% CI 1.23–1.94, comparing adolescents at the 85th–94th percentile for BMI to those at the 4th–49th percentile) (364).

In summary, evidence from prospective studies seems to converge at a positive association between aspects of body size in childhood and higher risk of islet autoimmunity and/or type 1 diabetes. However, many studies differ in the timing and type of measurements, and magnitudes of associations (typically a 20% increase in risk for each standard deviation increase) seem too small for individual risk prediction and to plausibly target in future intervention trials to test the causality of this apparent association.

## Toxins and Chemical Compounds

Chemical compounds and toxicants found in foods, water, or even air may activate autoimmune mechanisms or have cytotoxic effects on beta cells, as suggested in animal models. For instance, multiple low doses of the cytotoxic compound streptozotocin, which enters beta cells via glucose transporters, cause an apparent immune-mediated diabetes in rodents (365,366,367). Proof of principle from humans comes from accidental intake of large doses of the now-banned rodenticide Vacor (368). Most environmental chemicals that humans are exposed to in daily life are not likely to act via these mechanisms, although different mechanisms have been proposed for common environmental chemicals (369). Here, we review epidemiologic studies in humans, with a focus on prospective studies or those using individual level (rather than ecologic) designs, and biomarkers of exposure. Maternal smoking during pregnancy is reviewed in the Prenatal and Perinatal Factors section.

Intrauterine exposure to toxicants was tested in a Swedish study of 150 cases of type 1 diabetes and matched controls, nested within a cohort of births in Malmö (370). Two compounds measured in maternal serum at delivery (polychlorinated biphenyl [PCB]-153 and the major DDT metabolite p,p′-DDE) were used as biomarkers of persistent organochlorine pollutants, and these compounds showed inverse, but nonsignificant, association with type 1 diabetes (OR 0.73, 95% CI 0.42–1.27 and OR 0.56, 95% CI 0.29–1.08, comparing the highest quartile with the three lowest, respectively for the two biomarkers) (370). Also, the concentration of these toxicants in blood decreased with increasing calendar year at delivery in the period 1970–1990 (370), as has been seen for several other environmental chemicals (reviewed in (34)).

In analyses involving 30–40 cases of islet autoimmunity (at least one islet autoantibody) from two Finnish cohorts, no association was found between plasma concentrations of toxicants and risk of islet autoimmunity (371). Plasma levels of 13 persistent organic pollutants and 14 per- and polyfluorinated substances were analyzed in cord blood and plasma samples taken at age 12 months from the Finnish Dietary Intervention Trial for the Prevention of Type 1 Diabetes (FINDIA) cohort and in samples taken at age 48 months from DIABIMMUNE. Of 25 assayed toxicants, 17 were measurable in the 12-month samples and 14 in the 48-month samples, and six analytes were above assay detection limits in at least some cord blood samples. Several chemicals showed association with place of residence and with breastfeeding (in postnatal samples), but not with islet autoimmunity. Among the 80 statistical tests done for different compounds and time of sample, only two showed nominal borderline significance (not corrected for multiple testing), of which one showed weak inverse association (hexachlorobenzene at age 12 months, after adjustment for breastfeeding) and the other a positive association (perfluorodecanoic acid at age 48 months, but the association was not significant after adjustment for breastfeeding) (371). We conclude, as the authors did, that there is no evidence for an association between early chemical exposures and risk of islet autoimmunity.

A retrospective case-control study measured three organochloride pesticides (p,p′-DDE, trans-Nonachlor, and hexachlorobenzene) and two PCBs (PCB-28 and PCB-153) in children and youth from Colorado and South Carolina (372). The type 1 diabetes group was divided in two groups: insulin sensitive (n=182) and insulin resistant (n=148) with median diabetes duration of 1.8 and 3.6 years, respectively. Controls (n=112) were selected from primary health care providers in the same area with similar age (372). The sum of all five persistent organic pollutants (analyzed as tertiles) showed no significant association comparing either of the two groups with controls; similar results were found for the sum of the three organochloride pesticides or the sum of the two PCBs. Of a total of 16 statistical tests, three were nominally significant (uncorrected p<0.05), but none were significant if correcting for multiple testing. Furthermore, concentrations of these chemical compounds were highest in subjects with lower BMI, which was higher in controls than in insulin-sensitive type 1 diabetes cases and apparently not adjusted for in the analysis. The overall result from this study is, therefore, no significant association, and it may be biased by adiposity.

Among a handful of other retrospective case-control studies of different environmental chemicals measured in biospecimens, some showed significant positive associations and others significant inverse associations, as reviewed by Howard (373). Although differing in methodology and chemicals measured, we conclude that the available studies do not provide any evidence for association between biomarkers of environmental toxicants and risk of type 1 diabetes.

Air pollution has been suggestively associated with type 1 diabetes incidence, including in a 2015 study from Malmö of maternal exposure during pregnancy (374) and other studies reviewed by Howard (373). Although attempts were made to model components of air pollution at the place of residence of the study participants, the true individual exposure is very difficult to measure in such studies, which remain susceptible to ecologic bias. A large study from the United Kingdom in 2020 took a broad approach to exposures of different kinds (375). Among the findings that were significant after correcting for multiple testing (53 exposures in total) were four measures of air pollution (particulate matter, nitrogen dioxide, nitrogen oxides, carbon monoxide). Notably, all of these measures were inversely associated with incidence of type 1 diabetes (375). However, all of the studies of air pollution were ecologic or semi-ecologic, modelling air pollution at the area-level of residence with ample opportunities for misclassification, as well as confounding by ethnicity, socioeconomic status, and other factors that cannot be controlled in ecological studies (376). The heterogeneity of results and methodological weaknesses in available studies make it difficult to conclude that there is any true association.

## Psychosocial and Socioeconomic Factors

### Psychological Stress

Plausible mechanisms have been proposed to link various aspects of psychological stress in children or mothers during the perinatal period and immunity in children, potentially influencing islet autoimmunity (reviewed in (377)). A potential role of psychological stress in the etiology of type 1 diabetes has been suggested by case reports and small case-control studies dating back at least to the 1970s, and some more recent cohort studies have suggested a possible association (377). Stress is of course difficult to measure objectively, and various measures or proxies of stress have been assessed in different studies. Those studies investigating islet autoimmunity as the outcome often focused on maternal stress in pregnancy, which will often carry over to stress experienced by the child in early life. Some of the first prospective data in the field came from the Swedish All Babies in Southeast Sweden (ABIS) study. Two papers by Sepa et al. in 2005 reported associations between parenting stress or the mother’s experience of divorce or violence with positivity for GAD or IA-2 autoantibodies in the child at age 12 months or 30 months (378,379). The outcome in these studies was positivity for a single (of two measured) islet autoantibody, with the internal 95th percentile as the cutoff with no confirmation in the same or repeated samples; thus, this analysis is likely to contain many false positives (380). Later follow-up of ABIS provided more robust tests of the potential association between stress and the risk of clinical type 1 diabetes, as identified in nationwide registries and, thus, not susceptible to differential loss to follow-up. Among approximately 10,000 children born in 1999, 58 developed type 1 diabetes by 2012, after assessment of family psychological stress using parental questionnaires (serious life events, parenting stress, parental worries, and the parent’s social support) (381). Childhood experience of a serious life event was associated with a higher risk of future diagnosis of type 1 diabetes (HR 3.0, 95% CI 1.6–5.6) (381).

The Swedish DiPiS study recorded stressful life events in questionnaires to parents when the child was ages 2 months (n=23,187) and 2 years (n=3,784), of whom 166 and 79 subsequently developed clinical type 1 diabetes, respectively (382). Experience of a serious life event during the child’s first 2 years of life was associated with a significantly increased risk of type 1 diabetes (HR 1.67, 95% CI 1.1–2.7) (382).

In the TEDDY study, at least one life event during pregnancy was experienced by 64% of mothers, and this experience was not associated with risk of islet autoimmunity (HR 0.99, 95% CI 0.82–1.18) (383). No consistent dose-response association was observed with increasing number of life events experienced by the mother. When subdivided into six categories, a serious interpersonal life event (such as divorce) tended to be associated with a slightly increased risk, while for instance, job-related stress in pregnancy tended to be inversely associated with risk of islet autoimmunity. Further subgroup analyses gave a range of suggestive associations with subgroups of islet autoimmunity (autoantibodies to insulin first vs. GAD first) or in subgroups defined by susceptibility genetic variants, and associations were often in opposite directions in subgroups, making interpretation difficult (383).

Finally, two series of Danish register-based studies by two different groups have investigated the association between aspects of stress and risk of type 1 diabetes (384,385,386,387). In an analysis of more than 1.5 million births, Virk et al. reported in 2010 that children of mothers experiencing the death of a partner or child in the periconceptional period had an increased risk of type 1 diabetes (RR 2.03, 95% CI 1.22–3.38), with the strongest associations seen in females (384). In a similar register-based cohort, Virk et al. reported in 2016 that a child’s own experience of bereavement (death of a family member) at age ≥5 years was associated with a slightly increased risk of type 1 diabetes. Over 6,000 children in the cohort developed type 1 diabetes, and bereavement after age 11 years was associated with an incidence rate ratio (IRR) of 1.28 (95% CI 1.08–1.51) (385). In a subsequent analysis of linked Danish registries, Bengtsson et al. investigated early life adversities in relation to risk of type 1 diabetes (386,387). Using multistate modeling of accumulated childhood adversities, these analyses showed a relatively weak association with increased risk of type 1 diabetes in females (HR per adversity increase: 1.07, 95% CI 1.02–1.11) and no association in males (HR per adversity increase: 0.99, 95% CI 0.97–1.03) (386). In another analysis, Bengtsson et al. investigated five trajectory groups of adversity (characterized by either low adversity, early-life material deprivation, persistent material deprivation, loss or threat of loss in the family, or cumulative high adversity) among over a million children, of whom 5,619 developed type 1 diabetes during follow-up. In this analysis, only small differences were found between groups (387). Adversities included job loss and financial difficulties of the parents, which are partly related to socioeconomic status covered in the next subsection.

In summary, TEDDY reported no overall association between maternal life events and risk of islet autoimmunity, while two cohorts in Sweden with fewer than 100 type 1 diabetes cases found associations between life events and higher risk. Danish, large-scale, register-based analyses of quite extreme stresses, such as deaths of family members, gave partly inconsistent results, with the most recent and comprehensive analyses suggesting little or no association. While prospective evidence in this field has started to accumulate, inconsistencies and limited opportunities for pragmatic, targeted interventions in the future remain.

### Socioeconomic Factors

The incidence of childhood-onset type 1 diabetes varies widely among countries, and the disease tends to be more common in wealthier countries (388,389). Although such ecologic comparisons should be made with caution, it is of interest that many environmental exposures hypothesized to be risk factors for type 1 diabetes tend to be more common in children with low socioeconomic status. Socioeconomic status is multifaceted and context-dependent but may give hints toward potential mediating exposures to follow-up; however, surprisingly few high-quality studies attempting to link individual level socioeconomic status and risk of type 1 diabetes are available. In a 2023 comprehensive review, only a handful of prospective cohort studies were identified, and most did not study socioeconomic status as a primary exposure and did not adjust for ethnicity, maternal age, and smoking during pregnancy (390). Most studies with socioeconomic status had ecologic- or semi-ecologic designs,, where socioeconomic status was measured only as the average in the area of residence, a design that is highly susceptible to bias (390). Results among studies with area-based measures often found positive associations consistent with the worldwide impression across countries (390). However, individual-level studies typically found weaker associations, and results were inconsistent.

In a well-conducted, registry-based, nested case-control study in Washington state, maternal education showed a nonlinear association with type 1 diabetes, where both mid- and high-level education showed a significant, nearly twofold higher incidence of type 1 diabetes (RR 1.8 and 1.9, respectively) compared to children of mothers with low education (391).

A cohort study from Turin, Italy, also reported a non-linear association, with highest risk of type 1 diabetes in children of parents with highest education (highest of maternal or paternal education; RR 1.67 for age-group 4–14 years) (202). While the study from Washington state found that the medium-level maternal education group had type 1 diabetes risk equal to the high educational level, the Turin study showed that the medium-level parental education had similar risk to the low parental education group. A Norwegian, population-wide registry-based cohort of over one million children also reported a non-linear association with maternal education, but here, the relationship resembled an inverse U, with lower risk in those with highest maternal education compared with medium-level education (RR around 0.8) (206). The latter finding was consistent in other Scandinavian registry-based cohorts, although these reported only unadjusted results because parental education was used as a covariate in other analyses (390). In the Norwegian study, paternal education or occupation was not associated with childhood-onset type 1 diabetes (206).

## Prenatal and Perinatal Factors

While autoimmunity in non-monogenic type 1 diabetes is never present at birth, in utero and perinatal exposures may influence development of islet autoimmunity or even progression to type 1 diabetes (392). Here, we review perinatal factors other than in utero infections and nutritional factors that were covered in previous sections.

Higher maternal age at delivery has been associated with a slightly higher risk of type 1 diabetes since the 1980s (393,394), showing a relatively consistent 10%–20% increased risk in offspring of the oldest mothers in a harmonized meta-analysis (392). The mechanisms explaining this association remain unclear.

Maternal pre-pregnancy obesity was associated with an approximately 50% increased incidence of type 1 diabetes in children in the Norwegian MoBa and Danish DNBC cohort (395). Similar findings have been seen in a study from the United States (391) and in other studies (systematically reviewed in (396)), although maternal BMI was not associated with islet autoimmunity in the DIPP study (397). Furthermore, as Magnus et al. in the MoBa and DNBC study also found a similar association with paternal obesity, used as a negative control, it does not seem plausible that the maternal obesity association represents a proxy for a causal in utero exposure (395).

A frequently cited potential risk factor for type 1 diabetes is cesarean section, which showed a pooled odds ratio of 1.2 in an individual-level meta-analysis (398). This association has been widely believed to be mediated by aspects of the child’s microbiota, but other studies have shown that the association may be even weaker than 1.2 or possibly nonexistent, when accounting for additional confounding factors (343,399,400).

Smoking in pregnancy is one of the most consistent associations across several prospective studies and is paradoxically associated with a slightly lower risk of type 1 diabetes in children. The average relative risk for persistent smoking throughout pregnancy is around 0.7 based on several cohort studies and nested case-control studies from the United States and other parts of the world (391,401,402,403,404,405). This inverse association persists after adjusting for birth weight (402,404). Consistent associations have been reported in studies using cotinine as a biomarker of nicotine (402) and in sibling design (403), which should account for at least some of the potentially confounding factors that may be involved.

Preterm birth was significantly associated with increased risk of type 1 diabetes in a systematic review and meta-analysis of 18 studies (OR 1.18, 95% CI 1.11–1.25) (406). Subgroup analyses suggested the association was present both in case-control studies (OR 1.16, 95% CI 1.06–1.26) and cohort studies (RR 1.20, 95% CI 1.11–1.29). A large Swedish cohort study found an inverted U-shaped relation between gestational age and type 1 diabetes (400). Children born before the 33rd week or after the 40th week were at lowest risk, while those born between the 33rd and 36th weeks were at highest risk (RR 1.18, 95% CI 1.09–1.28), compared to those born at term. While these factors are unlikely to directly trigger islet autoimmunity, they may direct future research toward causal exposures.

Further evidence of fetal programming of type 1 diabetes risk comes from the still unexplained decreased type 1 diabetes risk in children of mothers with type 1 diabetes compared to children of fathers with type 1 diabetes (407,408). Most perinatal factors reviewed here are not likely to be directly causally related to type 1 diabetes but could provide clues for creative investigators to devise tests of novel hypotheses of specific factors operating in utero or in early life.

## Omics, Interactions, and the Exposome

Type 1 diabetes is likely a result of complex interplay between multiple genetic and environmental factors and timing of exposures. True associations may well be hidden in subgroups, unless these are investigated. However, investigators in a given study must strike a balance between missing important associations and testing too many associations, subgroups, and interactions, which may lead to chance findings because of multiplicity (multiple testing or overfitting), the inclusion of too many predictor variables leading to overly optimistic prediction (409). While such techniques as cross-validation and other resampling methods may aid in reducing overfitting in high-dimensional studies, independent validation remains the gold standard for ensuring robust, reproducible findings. Most machine learning algorithms used for high-dimensional data require sample sizes much larger than what are available even for the largest among the existing longitudinal birth cohort studies of islet autoimmunity and type 1 diabetes (410). Metabolomics and many other -omics data are plausibly influenced by diabetes, and associations may be due to reverse causation if measures are done at or after disease onset.

Again, prospective studies are essential, and we restrict our review in the next section to prospective studies. Many metabolites and epigenetic markers are influenced by a combination of genetic and environmental exposures, and accounting for genetic susceptibility and even integrating multiple -omics measures may be desirable with the above-mentioned limitations regarding multiplicity.

### Metabolomic Studies

Previously unknown pathways to type 1 diabetes can be discovered by analyzing changes in serum or plasma metabolites at multiple time points prior to development of islet autoimmunity and during progression to clinical diabetes. High-genetic-risk Finnish children followed since birth until diagnosis of type 1 diabetes had reduced serum levels of succinic acid and phosphatidylcholine already at birth; furthermore, levels of lysophosphatidylcholine increased months before seroconversion to islet autoantibodies but normalized after seroconversion (411). Higher levels of odd-chain triglycerides and polyunsaturated fatty acid-containing phospholipids predicted islet autoimmunity in German high-risk children (412). In addition, children developing islet autoimmunity before age 2 years had lower levels of methionine than those developing islet autoimmunity at older ages (412).

A Swedish cohort study analyzed 106 lipid metabolites from cord blood samples to identify possible risk markers for the early development of type 1 diabetes, while controlling for HLA genotype, sex, and date of birth, as well as mother’s age and gestational age (413). Lower levels of phospholipids (phosphatidylcholines, phosphatidylethanolamines, and sphingomyelins) predicted diabetes before age 4 years, while triglycerides predicted diabetes before age 2 years. Higher risk of diabetes associated with lower cord blood levels of choline-containing phospholipids was replicated in Finnish children (414). On the other hand, a Norwegian case-control study found no association between cord blood bile acids and other small polar metabolites and future type 1 diabetes (71).

The Finnish DIPP study reported amino acid dysregulation (lower levels of glutamic acid, aspartic acid, and tryptophan) preceding development of islet autoimmunity. Metabolites of microbial origin also differed between children who developed diabetes and controls (415), consistent with potential involvement of the gut bacteria in the etiology of type 1 diabetes. The international TEDDY study evaluated plasma metabolomic signatures from age 4 months until the appearance of islet autoimmunity. Distinct metabolomic signatures composed of dehydroascorbic acid, amino acids, and fatty acids were associated prospectively with development of islet autoimmunity. Reduced proline was associated with the appearance of autoantibodies against GAD, whereas reduced branched-chain amino acids, methionine and alanine, as well as fatty acids, preceded the appearance of antibodies against insulin (416). The existence of these distinct metabolic patterns for development of the autoantibodies supports the idea of distinct endotypes of type 1 diabetes (38,39). An unsupervised clustering analysis of temporal lipidome showed that reduced plasma ascorbic acid and cholesterol predicted the earlier endotype characterized by insulin autoantibodies and the HLA-DR4-DQ8 haplotype. On the other hand, reduced sphingomyelins at infancy predicted the later endotype characterized by GAD autoantibodies and the HLA-DR3-DQ2 haplotype (417). Lower plasma 25(OH)D levels predicted progression to type 1 diabetes in both endotypes, while lower diglycerides, lysophosphatidylcholines, triglycerides, and alanine predicted progression in the GAD autoantibody endotype. The apparent interactions between immune phenotypes, genotypes, and metabolomic profiles stimulated development of machine learning models integrating these predictors (418,419,420).

In the initial report from DAISY (420), among the strongest predictors of islet autoimmunity were changes in serum ascorbate and 3-methyl-oxobutyrate, while unsurprisingly, serum glucose and mannose were among the strongest predictors of progression to diabetes. In TEDDY, modeling identified a set of 18 genetic markers, gestational age, exposure to a prebiotic formula, and 22 metabolites and lipids (lipid oxidation, phospholipase A2 signaling, and pentose phosphate pathways) that predicted development of islet autoantibodies (418). In a separate machine learning-based analysis of 702 TEDDY participants positive for islet autoimmunity, metabolites measured at age 3, 6, or 9 months predicted progression to type 1 diabetes by age 6 years (419). The machine learning model, which included islet antibodies at age 9 months, genetic risk score, and gestational age, was highly predictive with AUC 0.84, even when reducing measurements to 3 and 9 months. Several predictive metabolites could be of dietary origin, such as piperidone and ascorbic acid. Interestingly, fructose, levoglucosan, glycerol alpha-phosphate, and xylulose were selected, suggesting altered carbohydrate metabolism in infancy as an important factor for progression to type 1 diabetes by age 6 years. Importantly, islet autoantibodies and HLA genotype remained the strongest contributors to AUC, and little improvement in AUC could be observed when additional features, such as metabolomics, were included in the model.

The metabolomic studies to date present several leads for a search for environmental factors that trigger islet autoimmunity and are involved in the increasing incidence of type 1 diabetes. The alterations in cord blood lipoprotein profiles suggest that the intrauterine environment may affect type 1 diabetes risk. Early infancy metabolomic changes may reflect specific alterations in the infant’s microbiome (421) or diet (422,423). Other lipidomic and metabolomic changes noted above that precede the development of autoimmunity may reflect the activation of proinflammatory and anti-inflammatory mechanisms in early islet autoimmunity.

While fascinating, these findings must be interpreted with caution as most studies to date have been very small and remain to be replicated. As understanding of the critical metabolic pathways expands, integration of metabolomic biomarkers with classical type 1 diabetes risk factors will improve disease prediction in persons at increased risk for type 1 diabetes.

### Gene-Environment Interactions

Inconsistencies in the associations between dietary factors and islet autoimmunity or type 1 diabetes across studies may be explained, in part, by methodologic differences in population selection and data collection. Another explanation is gene-environment interaction, where differences in the observed exposure associations may be due to differences in gene allele frequency across populations. There are several ways to explore gene-environment interaction in epidemiologic data, each dependent on the underlying hypothesis.

One hypothesis is that the effect of environmental risk factors may be stronger among individuals possessing increased genetic risk variants, whereby the odds ratio (or relative risk) is significantly different than 1 (i.e., associated) in those possessing the genetic risk variants, such as the HLA-DR risk genotypes, and null (i.e., not associated) in those without the variants, perhaps because it is easier to see the effect of the exposure in a genetically susceptible population. Alternatively, the aforementioned rise in type 1 diabetes incidence, coupled with data suggesting an increasing penetrance of moderate-risk HLA-DR genotypes, suggests that the pressures of an increasingly permissive environment may be more easily observed in children with moderate- or low-risk HLA-DR genotypes compared with high-risk genotypes.

In addition, one can examine a potential gene-environment interaction in more detail by dividing analyses into exposure-HLA combinations, with one risk group being those who have the exposure but not the HLA genotype, another risk group containing those who have the HLA genotype and not the exposure, and the putative highest risk group (i.e., representing the interaction) would be those with both the HLA genotype and the exposure. Each of these risk groups would be compared to the referent group, who are individuals with neither the HLA genotype nor the exposure. If the odds ratio in those with both the genetic variant and the exposure is greater than the product of the odds ratio for the exposure and odds ratio for the genotype, then the interaction is considered more than multiplicative.

Table 7 summarizes significant gene-environment interactions reported from cohort studies, primarily on nutritional factors. Several studies have examined potential interactions between HLA variants and dietary exposures. Stene et al. tested whether the effect of different dietary factors (use of cod liver oil and multivitamins by the mother during pregnancy, use of cod liver oil or vitamin D supplements in the first year of life, and exclusive breastfeeding for <3 months) differed across HLA risk groups and found no evidence of interaction, although power was limited (424). In DAISY, the hazard ratios for islet autoimmunity for early and late exposure to cereals in children with an HLA-DR3/4 genotype were greater than in children with the moderate- and low-risk HLA-DR genotypes, although the interaction term was only marginally significant (273). Studies from Colorado and Chile have indicated a more than multiplicative joint effect of HLA-DR risk and either short duration of exclusive breastfeeding (425) or early introduction of cow’s milk and solid foods (426). As an example, in the Colorado study, the odds ratio for type 1 diabetes for being HLA-DR3/4 in the absence of early exposure to solid foods was 3.1 (95% CI 1.4–7.2), the odds ratio for early exposure to solid foods in the absence of HLA-DR3/4 was 1.7 (95% CI 0.5–5.8), and the odds ratio for having both HLA-DR3/4 and early exposure to solid foods was 6.3 (95% CI 2.5–16.1) (426). In an analysis of the DIPP study, first exposure to solid foods at age 3–4 months (compared with after age 4 months) was associated with increased risk of islet autoimmunity only in those carrying the high-risk HLA-DR genotype (279). And finally, the previously mentioned association between early exposure (age <28 days) to probiotics from supplements and formula and decreased risk of islet autoimmunity was observed only in TEDDY children carrying the high-risk HLA-DR3/4 genotype (252).

The inconsistent findings with childhood cow’s milk consumption and risk of islet autoimmunity or type 1 diabetes may be due to the modifying effects of the underlying genetic profile. In DAISY, greater childhood cow’s milk protein intake (as a surrogate of total milk consumption) was associated with increased islet autoimmunity risk in children with low/moderate-risk HLA-DR genotypes (HR 1.41, 95% CI 1.08–1.84), but not in children with high-risk HLA-DR genotypes (294).

In addition to HLA, other type 1 diabetes candidate genes, such as INS, PTPN22, CTLA4, and IFIH1, have been explored for interactions with dietary exposures. In DIPP, an interaction was seen between early cow’s milk exposure, PTPN22, and appearance of islet autoimmunity, where the PTPN22 polymorphism was associated with the development of islet autoimmunity only in children exposed to cow’s milk formula prior to age 6 months (427).

Investigators have explored interactions with genes that are not candidate genes for type 1 diabetes but may be related to dietary exposures with regard to either metabolism or action. For example, omega-3 fatty acids may act as ligands for the nuclear receptor peroxisome proliferator-activated receptor-γ (PPARG) to promote anti-inflammatory actions. However, no evidence of interaction was found between the PPARG gene variant and cod liver oil intake on risk of type 1 diabetes in a Norwegian case-control study (428). Delta-6-desaturase, encoded by FADS2, and delta-5-desaturase, encoded by FADS1 (429), work in series to convert the omega-3 fatty acid ALA to the more anti-inflammatory fatty acid EPA. DAISY observed a strong interaction between dietary intake of ALA and FADS1 and FADS2 on risk of islet autoimmunity, where ALA intake was significantly more protective for islet autoimmunity in the presence of the increasing number of minor alleles at FADS1 rs174556 (p_interaction_=0.017), at FADS2 rs174570 (p_interaction_=0.016), and at FADS2 rs174583 (p_interaction_=0.045) (327). Thus, the putative protective effect of n-3 fatty acids on islet autoimmunity may result from a complex interaction between intake and genetically controlled fatty acid desaturation.

The small effect size of 25(OH)D and islet autoimmunity observed in the TEDDY and TRIGR studies reviewed in the Vitamin D section (i.e., OR 0.93 and 0.98 for a 5- and 1-unit difference, respectively) may be due to a failure to account for underlying genetic variation in the vitamin D pathway. Further analysis in TEDDY showed that the association between 25(OH)D and islet autoimmunity differs by the number of minor alleles in a SNP that marks the Apa1 restriction fragment length polymorphism (RFLP) in the vitamin D receptor gene (VDR). The protective effect of 25(OH)D is observed only in those with one or two minor alleles, with no effect of 25(OH)D in those with no minor alleles (Figure 5) (309).

Moreover, in MoBa, higher cord blood 25(OH)D was associated with a decreased risk of type 1 diabetes only in children that were homozygous for the G allele at the VDR variant rs1156882061 (430). This result suggests that the underlying susceptibility may be related to the ability to adequately use 25(OH)D, rather than the level itself. Interventions aimed at increasing 25(OH)D or attaining vitamin D sufficiency to prevent disease may not work in all children.

In BABYDIAB, cesarean section appeared to interact with immune response genes, such as IFIH1, where increased risk for type 1 diabetes was only seen in children who were delivered by cesarean section and had type 1 diabetes-susceptible IFIH1 genotypes (12-year risk, 9.1% vs. <3% for all other combinations, p<0.0001) (431). In Norway, mode of delivery was also found to interact with PTPN22, using a case-only approach; the relative risk for type 1 diabetes conferred by PTPN22 was 2.11 (95% CI 1.64–2.72) for those born vaginally and 0.99 (95% CI 0.50–1.99) for those born by cesarean section (p_(interaction)_=0.028) (432).

### Environment-Environment Interactions

Environmental exposures may interact, or act in concert, with other environmental exposures; however, examples of these observations are not prevalent in the scientific literature. Special requirements for replication of interactions occur, since the multiplicity of interactions quickly becomes overwhelming.

DAISY observed that a greater number of gastrointestinal illnesses was associated with an increased risk of islet autoimmunity but only among children who were exposed to gluten-containing grains (wheat or barley) either age <4 months (HR 1.37, 95% CI 1.22–1.55) or age ≥7 months (HR 1.12, 95% CI 1.05–1.19) (Table 6) (103).

Power to detect gene-environment or environment-environment interactions has been limited in most studies reported so far. Table 6 summarizes the significant associations with diet described above, while diet-gene interactions are summarized in Table 7. Prospective cohort studies have contributed enormously to our understanding of the natural history and risk factors for type 1 diabetes, particularly the largest of them—TEDDY. A variety of exposures appear to potentially trigger islet autoimmunity and to promote progression to clinical diabetes in some children; however, none of the current candidate risk factors seems to explain most of the risk. Future trials may need to take into account the genetic and environmental heterogeneity of this disease in developing personalized interventions.

### The Exposome

Given the lack of consistency among studies to date and the fact that we are still bewildered with regard to what type of environmental factors may explain the increasing incidence of type 1 diabetes over time (34), a possible path is to approach the concept of the exposome. This concept encompasses measurements of all internal and external exposures an individual experiences from fetal life throughout the life course (433,434,435). In the widest sense, the exposome encompasses multi-omics measurements, as well as responses to external exposures (435). With the risk of being unsurmountable, this approach intends to be hypothesis free but requires large samples sizes and replications to avoid chance findings. One advantage, at least in principle, is that the multiplicity is explicit, rather than hidden among investigators’ selective analyses. Albeit with the weakness of using ecological design, a large study of type 1 diabetes in 2020 has taken a step in this direction (375). Efforts have been initiated with funding from the European Union to study the exposome in birth cohorts, such as DIPP, MIDIA, DiPiS, MoBa, and others (436). Hopefully, these studies will complement TEDDY and other birth cohorts in the field.

## Conclusion

Despite years of studying potential non-genetic etiological factors for type 1 diabetes, including in multiple, well-conducted studies, few factors seem to be robustly associated with risk of islet autoimmunity or type 1 diabetes. Childhood obesity seems to be among the few factors consistently associated, but the magnitude of association seems too weak to explain the increasing incidence of type 1 diabetes observed in most populations. Complexities such as timing and interactions among multiple exposures, as well as methodological weaknesses of these studies, are possible explanations for these inconclusive results. Ultimately, randomized trials will be necessary to prove any causal effect of non-genetic factors on the etiology of type 1 diabetes and to implement prevention efforts to address these causes.

## List of Abbreviations

25(OH)D: 25-hydroxy vitamin D
ABIS: All Babies in Southeast Sweden study
ALA: alpha-linolenic acid
AUC: area under a (receiver operating characteristic) curve
BCG: Bacillus Calmette-Guérin
BMI: body mass index
CI: confidence interval
CMV: cytomegalovirus
COVID-19: coronavirus disease of 2019
DAISY: Diabetes Autoimmunity Study in the Young
DHA: docosahexaenoic acid
DiMe: Childhood Diabetes in Finland Study
DiPiS: Diabetes Prediction in Skåne study
DIPP: Diabetes Prediction and Prevention Study
DNBC: Danish National Birth Cohort
DPA: docosapentaenoic acid
EPA: eicosapentaenoic acid
FADS1: delta-5-desaturase gene
FADS2: delta-6 desaturase gene
GAD: glutamic acid decarboxylase
HLA: human leukocyte antigen
HR: hazard ratio
IA-2: insulinoma antigen 2
INS: insulin gene
MIDIA: Environmental Triggers of Type 1 Diabetes study
MoBa: Mother, Father and Child Cohort study
OR: odds ratio
PBMC: peripheral blood mononuclear cells
PCB: polychlorinated biphenyl
PPARG: peroxisome proliferator-activated receptor gamma
PTPN22: protein tyrosine phosphatase non-receptor type 22 gene
RR: relative risk
RT-PCR: reverse transcription-polymerase chain reaction
SARS-CoV-2: severe acute respiratory syndrome coronavirus 2
SNP: single nucleotide polymorphism
TEDDY: The Environmental Determinants of Diabetes in the Young study
TRIGR: Trial to Reduce IDDM in the Genetically at Risk
VDR: vitamin D receptor gene
ZnT8: zinc transporter 8

## Funding

Dr. Stene was supported by the European Union’s Horizon 2020 Research and Innovation Programme under Grant Agreement No: 874864, by The National Research Council of Norway (grant 221909/F20), and by the Norwegian Institute of Public Health. Drs. Rewers and Norris were supported by grants from the National Institute of Diabetes and Digestive and Kidney Diseases (DK032493, DK032083, DK049654, and DK104351) and by a grant from the JDRF (17-2013-535).

## Acknowledgments

The authors thank data owners who provided raw data for Figure 1: Professors I. Waernbaum and G. Dahlquist provided data from the Swedish Childhood Diabetes Registry, Professor T. Skrivarhaug provided data from the Norwegian Childhood Diabetes Registry, and Professor O. Cinek provided data from the Czech Childhood Diabetes Registry.

This is an update of: Rewers M, Stene LC, Norris JM: Risk Factors for Type 1 Diabetes. Chapter 11 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No, 17-1468, 2018, p. 11.1–11.29

## Article History

Received in final form on August 2, 2023.

## References

1 Rewers M, Stene LC, Norris JM. Risk Factors for Type 1 Diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018:11.1-11.29:chap 11. Accessed December 14, 2023. https://www.ncbi.nlm.nih.gov/books/NBK567965/
2 Mølbak AG, Christau B, Marner B, Borch-Johnsen K, Nerup J. Incidence of insulin-dependent diabetes mellitus in age groups over 30 years in Denmark. Diabet Med. 1994;11(7):650-655. doi:10.1111/j.1464-5491.1994.tb00327.x 7955989
3 Cartee AK, Owens LA, Lahr BD, Yawn BP, Murray JA, Kudva YC. Incidence of type 1 diabetes is not increasing in a population-based cohort in Olmsted County, Minnesota, USA. Mayo Clin Proc. 2016;91(8):1066-1073. doi:10.1016/j.mayocp.2016.05.019 27492913
4 Weng J, Zhou Z, Guo L, et al. Incidence of type 1 diabetes in China, 2010–13: population based study. BMJ. 2018;360:j5295. doi:10.1136/bmj.j5295 29298776
5 Gale EA. The rise of childhood type 1 diabetes in the 20th century. Diabetes. 2002;51(12):3353-3361. doi:10.2337/diabetes.51.12.3353 12453886
6 DIAMOND Project Group. Incidence and trends of childhood type 1 diabetes worldwide 1990–1999. Diabet Med. 2006;23(8):857-866. doi:10.1111/j.1464-5491.2006.01925.x 16911623
7 Vehik K, Hamman RF, Lezotte D, et al. Increasing incidence of type 1 diabetes in 0- to 17-year-old Colorado youth. Diabetes Care. 2007;30(3):503-509. doi:10.2337/dc06-1837 17327312
8 Divers J, Mayer-Davis EJ, Lawrence JM, et al. Trends in incidence of type 1 and type 2 diabetes among youths—selected counties and Indian reservations, United States, 2002–2015. MMWR Morb Mortal Wkly Rep. 2020;69(6):161-165. doi:10.15585/mmwr.mm6906a3 32053581
9 Tuomilehto J, Ogle GD, Lund-Blix NA, Stene LC. Update on worldwide trends in occurrence of childhood type 1 diabetes in 2020. Pediatr Endocrinol Rev. 2020;17(Suppl 1):198-209. doi:10.17458/per.vol17.2020.tol.epidemiologychildtype1diabetes 32208564
10 Waernbaum I, Lind T, Möllsten A, Dahlquist G. The incidence of childhood-onset type 1 diabetes, time trends and association with the population composition in Sweden: a 40 year follow-up. Diabetologia. 2023;66(2):346-353. doi:10.1007/s00125-022-05816-0 36264296
11 Tuomilehto J, Karvonen M, Pitkäniemi J, et al. Record high incidence of type 1 (insulin-dependent) diabetes mellitus in Finnish children. Diabetologia. 1999;42(6):655-660. doi:10.1007/s001250051212 10382584
12 Harjutsalo V, Sund R, Knip M, Groop PH. Incidence of type 1 diabetes in Finland. JAMA. 2013;310(4):427-428. doi:10.1001/jama.2013.8399 23917294
13 Parviainen A, But A, Siljander H, Knip M, Finnish Pediatric Diabetes Register. Decreased incidence of type 1 diabetes in young Finnish children. Diabetes Care. 2020;43(12):2953-2958. doi:10.2337/dc20-0604 32998988
14 Joner G, Søvik O. Increasing incidence of diabetes mellitus in Norwegian children 0–14 years of age 1973–1982. Diabetologia. 1989;32(2):79-83. doi:10.1007/BF00505178 2721842
15 Skrivarhaug T, Stene LC, Drivvoll AK, Strøm H, Joner G. Incidence of type 1 diabetes in Norway among children aged 0–14 years between 1989 and 2012: has the incidence stopped rising? Results from the Norwegian Childhood Diabetes Registry. Diabetologia. 2014;57(1):57-62. doi:10.1007/s00125-013-3090-y 24149838
16 Patterson CC, Harjutsalo V, Rosenbauer J, et al. Trends and cyclical variation in the incidence of childhood type 1 diabetes in 26 European centres in the 25 year period 1989–2013: a multicentre prospective registration study. Diabetologia. 2019;62(3):408-417. doi:10.1007/s00125-018-4763-3 30483858
17 Haynes A, Bulsara MK, Bergman P, et al. Incidence of type 1 diabetes in 0 to 14 year olds in Australia from 2002 to 2017. Pediatr Diabetes. 2020;21(5):707-712. doi:10.1111/pedi.13025 32304132
18 Ehehalt S, Neu A, Michaelis D, et al. Incidence of type 1 diabetes in childhood before and after the reunification of Germany—an analysis of epidemiological data, 1960–2006. Exp Clin Endocrinol Diabetes. 2012;120(8):441-444. doi:10.1055/s-0032-1309045 22576256
19 Kamrath C, Rosenbauer J, Eckert AJ, et al. Incidence of type 1 diabetes in children and adolescents during the COVID-19 pandemic in Germany: results from the DPV registry. Diabetes Care. 2022;45(8):1762-1771. doi:10.2337/dc21-0969 35043145
20 Cinek O, Kulich M, Sumnik Z. The incidence of type 1 diabetes in young Czech children stopped rising. Pediatr Diabetes. 2012;13(7):559-563. doi:10.1111/j.1399-5448.2012.00858.x 22487027
21 Cinek O, Slavenko M, Pomahačová R, et al. Type 1 diabetes incidence increased during the COVID-19 pandemic years 2020–2021 in Czechia: results from a large population-based pediatric register. Pediatr Diabetes. 2022;23(7):956-960. doi:10.1111/pedi.13405 35982508
22 Wagenknecht LE, Lawrence JM, Isom S, et al. Trends in incidence of youth-onset type 1 and type 2 diabetes in the USA, 2002–18: results from the population-based SEARCH for Diabetes in Youth study. Lancet Diabetes Endocrinol. 2023;11(4):242-250. doi:10.1016/S2213-8587(23)00025-6 36868256
23 Niar S, Naceur M, Bessahraaoui M, et al. Epidemiology of type 1 diabetes in children in the province of Oran (Algeria), from 1975 to 2014 [In French]. Médicine des Maladies Métaboliques. 2015;9(5):529-532. doi:10.1016/S1957-2557(15)30212-1
24 Wacher NH, Gómez-Diaz RA, Ascencio-Montiel IJ, Rascón-Pacheco RA, Aguilar-Salinas CA, Borja-Aburto VH. Type 1 diabetes incidence in children and adolescents in Mexico: data from a nation-wide institutional register during 2000–2018. Diabetes Res Clin Pract. 2020;159:107949. doi:10.1016/j.diabres.2019.107949 31794808
25 Kawasaki E, Matsuura N, Eguchi K. Type 1 diabetes in Japan. Diabetologia. 2006;49(5):828-836. doi:10.1007/s00125-006-0213-8 16568259
26 Onda Y, Sugihara S, Ogata T, et al. Incidence and prevalence of childhood-onset type 1 diabetes in Japan: the T1D Study. Diabet Med. 2017;34(7):909-915. doi:10.1111/dme.13295 27925270
27 Rewers M, LaPorte RE, Walczak M, Dmochowski K, Bogaczynska E. Apparent epidemic of insulin-dependent diabetes mellitus in Midwestern Poland. Diabetes. 1987;36(1):106-113. doi:10.2337/diab.36.1.106 3792661
28 Fleegler FM, Rogers KD, Drash A, Rosenbloom AL, Travis LB, Court JM. Age, sex, and season of onset of juvenile diabetes in different geographic areas. Pediatrics. 1979;63(3):374-379. doi:10.1542/peds.63.3.374 440839
29 Nathanson N, Kew OM. From emergence to eradication: the epidemiology of poliomyelitis deconstructed. Am J Epidemiol. 2010;172(11):1213-1229. doi:10.1093/aje/kwq320 20978089
30 Insel RA, Dunne JL, Atkinson MA, et al. Staging presymptomatic type 1 diabetes: a scientific statement of JDRF, the Endocrine Society, and the American Diabetes Association. Diabetes Care. 2015;38(10):1964-1974. doi:10.2337/dc15-1419 26404926
31 Ziegler AG, Rewers M, Simell O, et al. Seroconversion to multiple islet autoantibodies and risk of progression to diabetes in children. JAMA. 2013;309(23):2473-2479. doi:10.1001/jama.2013.6285 23780460
32 Krischer JP, Liu X, Lernmark Å, et al. The influence of type 1 diabetes genetic susceptibility regions, age, sex, and family history on the progression from multiple autoantibodies to type 1 diabetes: a TEDDY study report. Diabetes. 2017;66(12):3122-3129. doi:10.2337/db17-0261 28903990
33 Vehik K, Lynch KF, Schatz DA, et al. Reversion of b-cell autoimmunity changes risk of type 1 diabetes: TEDDY Study. Diabetes Care. 2016;39(9):1535-1542. doi:10.2337/dc16-0181 27311490
34 Norris JM, Johnson RK, Stene LC. Type 1 diabetes—early life origins and changing epidemiology. Lancet Diabetes Endocrinol. 2020;8(3):226-238. doi:10.1016/s2213-8587(19)30412-7 31999944
35 Krischer JP, Lynch KF, Schatz DA, et al. The 6 year incidence of diabetes-associated autoantibodies in genetically at-risk children: the TEDDY study. Diabetologia. 2015;58(5):980-987. doi:10.1007/s00125-015-3514-y 25660258
36 Krischer JP, Lynch KF, Lernmark Å, et al. Genetic and environmental interactions modify the risk of diabetes-related autoimmunity by 6 years of age: the TEDDY study. Diabetes Care. 2017;40(9):1194-1202. doi:10.2337/dc17-0238 28646072
37 Krischer JP, Liu X, Lernmark Å, et al. Predictors of the initiation of islet autoimmunity and progression to multiple autoantibodies and clinical diabetes: the TEDDY study. Diabetes Care. 2022;45(10):2271-2281. doi:10.2337/dc21-2612 36150053
38 Leete P, Oram RA, McDonald TJ, et al. Studies of insulin and proinsulin in pancreas and serum support the existence of aetiopathological endotypes of type 1 diabetes associated with age at diagnosis. Diabetologia. 2020;63(6):1258-1267. doi:10.1007/s00125-020-05115-6 32172310
39 Smith MJ, Cambier JC, Gottlieb PA. Endotypes in T1D: B lymphocytes and early onset. Curr Opin Endocrinol Diabetes Obes. 2020;27(4):225-230. doi:10.1097/med.0000000000000547 32618634
40 Battaglia M, Ahmed S, Anderson MS, et al. Introducing the endotype concept to address the challenge of disease heterogeneity in type 1 diabetes. Diabetes Care. 2020;43(1):5-12. doi:10.2337/dc19-0880 31753960
41 Dabelea D, Mayer-Davis EJ, Saydah S, et al. Prevalence of type 1 and type 2 diabetes among children and adolescents from 2001 to 2009. JAMA. 2014;311(17):1778-1786. doi:10.1001/jama.2014.3201 24794371
42 Lawrence JM, Divers J, Isom S, et al. Trends in prevalence of type 1 and type 2 diabetes in children and adolescents in the US, 2001–2017. JAMA. 2021;326(8):717-727. doi:10.1001/jama.2021.11165 34427600
43 Imperatore G, Mayer-Davis EJ, Orchard TJ, Zhong VW. Prevalence and Incidence of Type 1 Diabetes Among Children and Adults in the United States and Comparison With Non-U.S. Countries. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018:2.1-2.17:chap 2. Accessed December 14, 2023. https://www.ncbi.nlm.nih.gov/books/NBK568003/
44 Wagener DK, Sacks JM, LaPorte RE, MacGregor JM. The Pittsburgh study of insulin-dependent diabetes mellitus. Risk for diabetes among relatives of IDDM. Diabetes. 1982;31(2):136-144. doi:10.2337/diab.31.2.136 6759229
45 Allen C, Palta M, D’Alessio DJ. Risk of diabetes in siblings and other relatives of IDDM subjects. Diabetes. 1991;40(7):831-836. doi:10.2337/diab.40.7.831 2060720
46 Steck AK, Barriga KJ, Emery LM, Fiallo-Scharer RV, Gottlieb PA, Rewers MJ. Secondary attack rate of type 1 diabetes in Colorado families. Diabetes Care. 2005;28(2):296-300. doi:10.2337/diacare.28.2.296 15677782
47 Redondo MJ, Rewers M, Yu L, et al. Genetic determination of islet cell autoimmunity in monozygotic twin, dizygotic twin, and non-twin siblings of patients with type 1 diabetes: prospective twin study. BMJ. 1999;318(7185):698-702. doi:10.1136/bmj.318.7185.698 10074012
48 Redondo MJ, Yu L, Hawa M, et al. Heterogeneity of type I diabetes: analysis of monozygotic twins in Great Britain and the United States. Diabetologia. 2001;44(3):354-362. doi:10.1007/s001250051626 11317668
49 Lorenzen T, Pociot F, Hougaard P, Nerup J. Long-term risk of IDDM in first-degree relatives of patients with IDDM. Diabetologia. 1994;37(3):321-327. doi:10.1007/bf00398061 8174848
50 O’Leary LA, Dorman JS, LaPorte RE, et al. Familial and sporadic insulin-dependent diabetes: evidence for heterogeneous etiologies? Diabetes Res Clin Pract. 1991;14(3):183-190. doi:10.1016/0168-8227(91)90019-a 1778111
51 Yu L, Cuthbertson DD, Eisenbarth GS, Krischer JP. Diabetes Prevention Trial 1: prevalence of GAD and ICA512 (IA-2) autoantibodies by relationship to proband. Ann N Y Acad Sci. 2002;958:254-258. doi:10.1111/j.1749-6632.2002.tb02981.x 12021118
52 Bonifacio E, Hummel M, Walter M, Schmid S, Ziegler AG. IDDM1 and multiple family history of type 1 diabetes combine to identify neonates at high risk for type 1 diabetes. Diabetes Care. 2004;27(11):2695-2700. doi:10.2337/diacare.27.11.2695 15505007
53 Redondo MJ, Onengut-Gumuscu S, Gaulton KJ. Genetics of Type 1 Diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/n/diaonline/genetics
54 Bjørnvold M, Undlien DE, Joner G, et al. Joint effects of HLA, INS, PTPN22 and CTLA4 genes on the risk of type 1 diabetes. Diabetologia. 2008;51(4):589-596. doi:10.1007/s00125-008-0932-0 18292987
55 Risch N. Assessing the role of HLA-linked and unlinked determinants of disease. Am J Hum Genet. 1987;40(1):1-14.3468804
56 Noble JA, Valdes AM, Cook M, Klitz W, Thomson G, Erlich HA. The role of HLA class II genes in insulin-dependent diabetes mellitus: molecular analysis of 180 Caucasian, multiplex families. Am J Hum Genet. 1996;59(5):1134-1148.8900244
57 Barrett JC, Clayton DG, Concannon P, et al. Genome-wide association study and meta-analysis find that over 40 loci affect risk of type 1 diabetes. Nat Genet. 2009;41(6):703-707. doi:10.1038/ng.381 19430480
58 Robertson CC, Inshaw JRJ, Onengut-Gumuscu S, et al. Fine-mapping, trans-ancestral and genomic analyses identify causal variants, cells, genes and drug targets for type 1 diabetes. Nat Genet. 2021;53(7):962-971. doi:10.1038/s41588-021-00880-5 34127860
59 Bell GI, Horita S, Karam JH. A polymorphic locus near the human insulin gene is associated with insulin-dependent diabetes mellitus. Diabetes. 1984;33(2):176-183. doi:10.2337/diab.33.2.176 6363172
60 Bottini N, Musumeci L, Alonso A, et al. A functional variant of lymphoid tyrosine phosphatase is associated with type I diabetes. Nat Genet. 2004;36(4):337-338. doi:10.1038/ng1323 15004560
61 Törn C, Hadley D, Lee HS, et al. Role of type 1 diabetes-associated SNPs on risk of autoantibody positivity in the TEDDY study. Diabetes. 2015;64(5):1818-1829. doi:10.2337/db14-1497 25422107
62 Beyerlein A, Bonifacio E, Vehik K, et al. Progression from islet autoimmunity to clinical type 1 diabetes is influenced by genetic factors: results from the prospective TEDDY study. J Med Genet. 2019;56(9):602-605. doi:10.1136/jmedgenet-2018-105532 30287597
63 Ilonen J, Kiviniemi M, Lempainen J, et al. Genetic susceptibility to type 1 diabetes in childhood—estimation of HLA class II associated disease risk and class II effect in various phases of islet autoimmunity. Pediatr Diabetes. 2016;17(Suppl 22):8-16. doi:10.1111/pedi.12327 27411431
64 Gorus FK, Balti EV, Messaaoui A, et al. Twenty-year progression rate to clinical onset according to autoantibody profile, age, and HLA-DQ genotype in a registry-based group of children and adults with a first-degree relative with type 1 diabetes. Diabetes Care. 2017;40(8):1065-1072. doi:10.2337/dc16-2228 28701370
65 Laine AP, Valta M, Toppari J, et al. Non-HLA gene polymorphisms in the pathogenesis of type 1 diabetes: phase and endotype specific effects. Front Immunol. 2022;13:909020. doi:10.3389/fimmu.2022.909020 35812428
66 Balke EM, Balti EV, Van der Auwera B, et al. Accelerated progression to type 1 diabetes in the presence of HLA-A*24 and -B*18 is restricted to multiple islet autoantibody-positive individuals with distinct HLA-DQ and autoantibody risk profiles. Diabetes Care. 2018;41(5):1076-1083. doi:10.2337/dc17-2462 29545461
67 Sharp SA, Weedon MN, Hagopian WA, Oram RA. Clinical and research uses of genetic risk scores in type 1 diabetes. Curr Opin Genet Dev. 2018;50:96-102. doi:10.1016/j.gde.2018.03.009 29702327
68 Redondo MJ, Gignoux CR, Dabelea D, et al. Type 1 diabetes in diverse ancestries and the use of genetic risk scores. Lancet Diabetes Endocrinol. 2022;10(8):597-608. doi:10.1016/S2213-8587(22)00159-0 35724677
69 Barker JM, Triolo TM, Aly TA, et al. Two single nucleotide polymorphisms identify the highest-risk diabetes HLA genotype: potential for rapid screening. Diabetes. 2008;57(11):3152-3155. doi:10.2337/db08-0605 18694972
70 Clayton DG. Prediction and interaction in complex disease genetics: experience in type 1 diabetes. PLoS Genet. 2009;5(7):e1000540. doi:10.1371/journal.pgen.1000540 19584936
71 Tapia G, Suvitaival T, Ahonen L, et al. Prediction of type 1 diabetes at birth: cord blood metabolites vs genetic risk score in the Norwegian Mother, Father, and Child Cohort. J Clin Endocrinol Metab. 2021;106(10):e4062-e4071. doi:10.1210/clinem/dgab400 34086903
72 Bonifacio E, Beyerlein A, Hippich M, et al. Genetic scores to stratify risk of developing multiple islet autoantibodies and type 1 diabetes: a prospective study in children. PLoS Med. 2018;15(4):e1002548. doi:10.1371/journal.pmed.1002548 29614081
73 Stene LC, Witsø E, Torjesen PA, et al. Islet autoantibody development during follow-up of high-risk children from the general Norwegian population from three months of age: design and early results from the MIDIA study. J Autoimmun. 2007;29(1):44-51. doi:10.1016/j.jaut.2007.04.003 17560077
74 Steck AK, Armstrong TK, Babu SR, Eisenbarth GS, Type 1 Diabetes Genetics Consortium. Stepwise or linear decrease in penetrance of type 1 diabetes with lower-risk HLA genotypes over the past 40 years. Diabetes. 2011;60(3):1045-1049. doi:10.2337/db10-1419 21307077
75 Vehik K, Hamman RF, Lezotte D, et al. Trends in high-risk HLA susceptibility genes among Colorado youth with type 1 diabetes. Diabetes Care. 2008;31(7):1392-1396. doi:10.2337/dc07-2210 18356404
76 Hermann R, Knip M, Veijola R, et al. Temporal changes in the frequencies of HLA genotypes in patients with type 1 diabetes—indication of an increased environmental pressure? Diabetologia. 2003;46(3):420-425. doi:10.1007/s00125-003-1045-4 12687342
77 Fourlanos S, Varney MD, Tait BD, et al. The rising incidence of type 1 diabetes is accounted for by cases with lower-risk human leukocyte antigen genotypes. Diabetes Care. 2008;31(8):1546-1549. doi:10.2337/dc08-0239 18487476
78 Resic-Lindehammer S, Larsson K, Örtqvist E, et al. Temporal trends of HLA genotype frequencies of type 1 diabetes patients in Sweden from 1986 to 2005 suggest altered risk. Acta Diabetol. 2008;45(4):231-235. doi:10.1007/s00592-008-0048-5 18769865
79 Spoletini M, Zampetti S, Campagna G, et al. Temporal trends of HLA, CTLA-4 and PTPN22 genotype frequencies among type 1 diabetes in Continental Italy. PLoS One. 2013;8(4):e61331. doi:10.1371/journal.pone.0061331 23613833
80 Gillespie KM, Bain SC, Barnett AH, et al. The rising incidence of childhood type 1 diabetes and reduced contribution of high-risk HLA haplotypes. Lancet. 2004;364(9446):1699-1700. doi:10.1016/s0140-6736(04)17357-1 15530631
81 Ziegler AG, Bonifacio E. Age-related islet autoantibody incidence in offspring of patients with type 1 diabetes. Diabetologia. 2012;55(7):1937-1943. doi:10.1007/s00125-012-2472-x 22289814
82 Ilonen J, Hammais A, Laine AP, et al. Patterns of beta-cell autoantibody appearance and genetic associations during the first years of life. Diabetes. 2013;62(10):3636-3640. doi:10.2337/db13-0300 23835325
83 Christau B, Kromann H, Andersen OO, et al. Incidence, seasonal and geographical patterns of juvenile-onset insulin-dependent diabetes mellitus in Denmark. Diabetologia. 1977;13(4):281-284. doi:10.1007/BF01223266 913920
84 Moltchanova EV, Schreier N, Lammi N, Karvonen M. Seasonal variation of diagnosis of type 1 diabetes mellitus in children worldwide. Diabet Med. 2009;26(7):673-678. doi:10.1111/j.1464-5491.2009.02743.x 19573115
85 Patterson CC, Gyürüs E, Rosenbauer J, et al. Seasonal variation in month of diagnosis in children with type 1 diabetes registered in 23 European centers during 1989–2008: little short-term influence of sunshine hours or average temperature. Pediatr Diabetes. 2015;16(8):573-580. doi:10.1111/pedi.12227 25316271
86 Samuelsson U, Carstensen J, Löfman O, Nordfeldt S. Seasonal variation in the diagnosis of type 1 diabetes in south-east Sweden. Diabetes Res Clin Pract. 2007;76(1):75-81. doi:10.1016/j.diabres.2006.07.023 16963147
87 Stene LC, Oikarinen S, Hyöty H, et al. Enterovirus infection and progression from islet autoimmunity to type 1 diabetes: the Diabetes and Autoimmunity Study in the Young (DAISY). Diabetes. 2010;59(12):3174-3180. doi:10.2337/db10-0866 20858685
88 Lynch KF, Lernmark B, Merlo J, et al. Cord blood islet autoantibodies and seasonal association with the type 1 diabetes high-risk genotype. J Perinatol. 2008;28(3):211-217. doi:10.1038/sj.jp.7211912 18273032
89 Vaiserman AM, Carstensen B, Voitenko VP, et al. Seasonality of birth in children and young adults (0–29 years) with type 1 diabetes in Ukraine. Diabetologia. 2007;50(1):32-35. doi:10.1007/s00125-006-0456-4 17093948
90 Kahn HS, Morgan TM, Case LD, et al. Association of type 1 diabetes with month of birth among U.S. youth: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2009;32(11):2010-2015. doi:10.2337/dc09-0891 19675199
91 McKinney PA, EURODIAB Seasonality of Birth Group. Seasonality of birth in patients with childhood type I diabetes in 19 European regions. Diabetologia. 2001;44(Suppl 3):B67-B74. doi:10.1007/pl00002957 11724420
92 Hedlund E, Ludvigsson J, Elding Larsson H, et al. Month of birth and the risk of developing type 1 diabetes among children in the Swedish national Better Diabetes Diagnosis Study. Acta Paediatr. 2022;111(12):2378-2383. doi:10.1111/apa.16426 35615774
93 Lönnrot M, Lynch K, Elding Larsson H, et al. A method for reporting and classifying acute infectious diseases in a prospective study of young children: TEDDY. BMC Pediatr. 2015;15:24. doi:10.1186/s12887-015-0333-8 25884839
94 Cohen C, Kleynhans J, Moyes J, et al. Asymptomatic transmission and high community burden of seasonal influenza in an urban and a rural community in South Africa, 2017–18 (PHIRST): a population cohort study. Lancet Glob Health. 2021;9(6):e863-e874. doi:10.1016/S2214-109X(21)00141-8 34019838
95 McNab F, Mayer-Barber K, Sher A, Wack A, O’Garra A. Type I interferons in infectious disease. Nat Rev Immunol. 2015;15(2):87-103. doi:10.1038/nri3787 25614319
96 Gamble DR. Relation of antecedent illness to development of diabetes in children. Br Med J. 1980;281(6233):99-101. doi:10.1136/bmj.281.6233.99 7427231
97 Gamble DR, Kinsley ML, FitzGerald MG, Bolton R, Taylor KW. Viral antibodies in diabetes mellitus. Br Med J. 1969;3(5671):627-630. doi:10.1136/bmj.3.5671.627 5811681
98 Rasmussen T, Witsø E, Tapia G, Stene LC, Rønningen KS. Self-reported lower respiratory tract infections and development of islet autoimmunity in children with the type 1 diabetes high-risk HLA genotype: the MIDIA study. Diabetes Metab Res Rev. 2011;27(8):834-837. doi:10.1002/dmrr.1258 22069269
99 Beyerlein A, Wehweck F, Ziegler AG, Pflueger M. Respiratory infections in early life and the development of islet autoimmunity in children at increased type 1 diabetes risk: evidence from the BABYDIET study. JAMA Pediatr. 2013;167(9):800-807. doi:10.1001/jamapediatrics.2013.158 23818010
100 Lönnrot M, Lynch KF, Elding Larsson H, et al. Respiratory infections are temporally associated with initiation of type 1 diabetes autoimmunity: the TEDDY study. Diabetologia. 2017;60(10):1931-1940. doi:10.1007/s00125-017-4365-5 28770319
101 Beyerlein A, Donnachie E, Jergens S, Ziegler AG. Infections in early life and development of type 1 diabetes. JAMA. 2016;315(17):1899-1901. doi:10.1001/jama.2016.2181 27139064
102 Tapia G, Størdal K, Mårild K, et al. Antibiotics, acetaminophen and infections during prenatal and early life in relation to type 1 diabetes. Int J Epidemiol. 2018;47(5):1538-1548. doi:10.1093/ije/dyy092 29868838
103 Snell-Bergeon JK, Smith J, Dong F, et al. Early childhood infections and the risk of islet autoimmunity: the Diabetes Autoimmunity Study in the Young (DAISY). Diabetes Care. 2012;35(12):2553-2558. doi:10.2337/dc12-0423 23043167
104 Cardwell CR, Carson DJ, Patterson CC. No association between routinely recorded infections in early life and subsequent risk of childhood-onset type 1 diabetes: a matched case-control study using the UK General Practice Research Database. Diabet Med. 2008;25(3):261-267. doi:10.1111/j.1464-5491.2007.02351.x 18201209
105 Hippich M, Oleynik A, Jain K, et al. Searching peripheral blood mononuclear cells of children with viral respiratory tract infections preceding islet autoimmunity for viruses by high-throughput sequencing. Acta Diabetol. 2018;55(8):881-884. doi:10.1007/s00592-018-1138-7 29687279
106 Nekoua MP, Alidjinou EK, Hober D. Persistent coxsackievirus B infection and pathogenesis of type 1 diabetes mellitus. Nat Rev Endocrinol. 2022;18(8):503-516. doi:10.1038/s41574-022-00688-1 35650334
107 Petzold A, Solimena M, Knoch KP. Mechanisms of beta cell dysfunction associated with viral infection. Curr Diab Rep. 2015;15(10):73. doi:10.1007/s11892-015-0654-x 26280364
108 Isaacs SR, Foskett DB, Maxwell AJ, et al. Viruses and type 1 diabetes: from enteroviruses to the virome. Microorganisms. 2021;9(7):1519. doi:10.3390/microorganisms9071519 34361954
109 Serreze DV, Ottendorfer EW, Ellis TM, Gauntt CJ, Atkinson MA. Acceleration of type 1 diabetes by a coxsackievirus infection requires a preexisting critical mass of autoreactive T-cells in pancreatic islets. Diabetes. 2000;49(5):708-711. doi:10.2337/diabetes.49.5.708 10905477
110 Horwitz MS, Fine C, Ilic A, Sarvetnick N. Requirements for viral-mediated autoimmune diabetes: beta-cell damage and immune infiltration. J Autoimmun. 2001;16(3):211-217. doi:10.1006/jaut.2000.0486 11334485
111 Christen U, Edelmann KH, McGavern DB, et al. A viral epitope that mimics a self antigen can accelerate but not initiate autoimmune diabetes. J Clin Invest. 2004;114(9):1290-1298. doi:10.1172/JCI22557 15520861
112 Drescher KM, Kono K, Bopegamage S, Carson SD, Tracy S. Coxsackievirus B3 infection and type 1 diabetes development in NOD mice: insulitis determines susceptibility of pancreatic islets to virus infection. Virology. 2004;329(2):381-394. doi:10.1016/j.virol.2004.06.049 15518817
113 International Committee on Taxonomy of Viruses: ICTV. Current ICTV Taxonomy Release: Taxonomy Browser. Accessed 2023, https://ictv.global/taxonomy
114 Baggen J, Thibaut HJ, Strating J, van Kuppeveld FJM. The life cycle of non-polio enteroviruses and how to target it. Nat Rev Microbiol. 2018;16(6):368-381. doi:10.1038/s41579-018-0005-4 29626210
115 Tapparel C, Siegrist F, Petty TJ, Kaiser L. Picornavirus and enterovirus diversity with associated human diseases. Infect Genet Evol. 2013;14:282-293. doi:10.1016/j.meegid.2012.10.016 23201849
116 Yoon JW, Austin M, Onodera T, Notkins AL. Isolation of a virus from the pancreas of a child with diabetic ketoacidosis. N Engl J Med. 1979;300(21):1173-1179. doi:10.1056/NEJM197905243002102 219345
117 Tracy S, Drescher KM, Chapman NM. Enteroviruses and type 1 diabetes. Diabetes Metab Res Rev. 2011;27(8):820-823. doi:10.1002/dmrr.1255 22069266
118 Hyöty H. Viruses in type 1 diabetes. Pediatr Diabetes. 2016;17(Suppl 22):56-64. doi:10.1111/pedi.12370 27411438
119 Richardson SJ, Willcox A, Bone AJ, Foulis AK, Morgan NG. The prevalence of enteroviral capsid protein vp1 immunostaining in pancreatic islets in human type 1 diabetes. Diabetologia. 2009;52(6):1143-1151. doi:10.1007/s00125-009-1276-0 19266182
120 Krogvold L, Edwin B, Buanes T, et al. Detection of a low-grade enteroviral infection in the islets of Langerhans of living patients newly diagnosed with type 1 diabetes. Diabetes. 2015;64(5):1682-1687. doi:10.2337/db14-1370 25422108
121 Oikarinen M, Laiho JE, Oikarinen S, et al. Detection of enterovirus protein and RNA in multiple tissues from nPOD organ donors with type 1 diabetes. bioRxiv. 2018:459347. doi:10.1101/459347
122 Geravandi S, Richardson S, Pugliese A, Maedler K. Localization of enteroviral RNA within the pancreas in donors with T1D and T1D-associated autoantibodies. Cell Rep Med. 2021;2(8):100371. doi:10.1016/j.xcrm.2021.100371 34467248
123 Green J, Casabonne D, Newton R. Coxsackie B virus serology and type 1 diabetes mellitus: a systematic review of published case-control studies. Diabet Med. 2004;21(6):507-514. doi:10.1111/j.1464-5491.2004.01182.x 15154932
124 Oikarinen S, Tauriainen S, Hober D, et al. Virus antibody survey in different European populations indicates risk association between coxsackievirus B1 and type 1 diabetes. Diabetes. 2014;63(2):655-662. doi:10.2337/db13-0620 24009257
125 Stene LC, Rewers M. Immunology in the clinic review series; focus on type 1 diabetes and viruses: the enterovirus link to type 1 diabetes: critical review of human studies. Clin Exp Immunol. 2012;168(1):12-23. doi:10.1111/j.1365-2249.2011.04555.x 22385232
126 Lönnrot M, Salminen K, Knip M, et al. Enterovirus RNA in serum is a risk factor for beta-cell autoimmunity and clinical type 1 diabetes: a prospective study. Childhood Diabetes in Finland (DiMe) Study Group. J Med Virol. 2000;61(2):214-220. doi:10.1002/(SICI)1096-9071(200006)61:2<214::AID-JMV7>3.0.CO;2-9 10797377
127 Oikarinen S, Martiskainen M, Tauriainen S, et al. Enterovirus RNA in blood is linked to the development of type 1 diabetes. Diabetes. 2011;60(1):276-279. doi:10.2337/db10-0186 20943747
128 Prather SL, Dagan R, Jenista JA, Menegus MA. The isolation of enteroviruses from blood: a comparison of four processing methods. J Med Virol. 1984;14(3):221-227. doi:10.1002/jmv.1890140305 6094721
129 Schulte BM, Bakkers J, Lanke KH, et al. Detection of enterovirus RNA in peripheral blood mononuclear cells of type 1 diabetic patients beyond the stage of acute infection. Viral Immunol. 2010;23(1):99-104. doi:10.1089/vim.2009.0072 20121407
130 Sioofy-Khojine AB, Richardson SJ, Locke JM, et al. Detection of enterovirus RNA in peripheral blood mononuclear cells correlates with the presence of the predisposing allele of the type 1 diabetes risk gene IFIH1 and with disease stage. Diabetologia. 2022;65(10):1701-1709. doi:10.1007/s00125-022-05753-y 35867130
131 Vehik K, Lynch KF, Wong MC, et al. Prospective virome analyses in young children at increased genetic risk for type 1 diabetes. Nat Med. 2019;25(12):1865-1872. doi:10.1038/s41591-019-0667-0 31792456
132 Salminen KK, Vuorinen T, Oikarinen S, et al. Isolation of enterovirus strains from children with preclinical type 1 diabetes. Diabet Med. 2004;21(2):156-164. doi:10.1111/j.1464-5491.2004.01097.x 14984451
133 Simonen-Tikka ML, Pflueger M, Klemola P, et al. Human enterovirus infections in children at increased risk for type 1 diabetes: the Babydiet study. Diabetologia. 2011;54(12):2995-3002. doi:10.1007/s00125-011-2305-3 21932150
134 Tapia G, Cinek O, Rasmussen T, et al. Human enterovirus RNA in monthly fecal samples and islet autoimmunity in Norwegian children with high genetic risk for type 1 diabetes: the MIDIA study. Diabetes Care. 2011;34(1):151-155. doi:10.2337/dc10-1413 20929993
135 Honkanen H, Oikarinen S, Nurminen N, et al. Detection of enteroviruses in stools precedes islet autoimmunity by several months: possible evidence for slowly operating mechanisms in virus-induced autoimmunity. Diabetologia. 2017;60(3):424-431. doi:10.1007/s00125-016-4177-z 28070615
136 Khetsuriani N, Lamonte-Fowlkes A, Oberst S, Pallansch MA, Centers for Disease Control and Prevention. Enterovirus surveillance—United States, 1970-2005. MMWR Surveill Summ. 2006;55(8):1-20. Accessed December 14, 2023. https://www.cdc.gov/mmwr/preview/mmwrhtml/ss5508a1.htm 16971890
137 Kim KW, Horton JL, Pang CNI, et al. Higher abundance of enterovirus A species in the gut of children with islet autoimmunity. Sci Rep. 2019;9(1):1749. doi:10.1038/s41598-018-38368-8 30741981
138 Thorsen J, Brejnrod A, Mortensen M, et al. Large-scale benchmarking reveals false discoveries and count transformation sensitivity in 16S rRNA gene amplicon data analysis methods used in microbiome studies. Microbiome. 2016;4(1):62. doi:10.1186/s40168-016-0208-8 27884206
139 Nearing JT, Douglas GM, Hayes MG, et al. Microbiome differential abundance methods produce different results across 38 datasets. Nat Commun. 2022;13(1):342. doi:10.1038/s41467-022-28034-z 35039521
140 Sadeharju K, Lönnrot M, Kimpimäki T, et al. Enterovirus antibody levels during the first two years of life in prediabetic autoantibody-positive children. Diabetologia. 2001;44(7):818-823. doi:10.1007/s001250100560 11508265
141 Salminen K, Sadeharju K, Lönnrot M, et al. Enterovirus infections are associated with the induction of β-cell autoimmunity in a prospective birth cohort study. J Med Virol. 2003;69(1):91-98. doi:10.1002/jmv.10260 12436483
142 Lempainen J, Tauriainen S, Vaarala O, et al. Interaction of enterovirus infection and cow’s milk-based formula nutrition in type 1 diabetes-associated autoimmunity. Diabetes Metab Res Rev. 2012;28(2):177-185. doi:10.1002/dmrr.1294 21922634
143 Füchtenbusch M, Irnstetter A, Jäger G, Ziegler AG. No evidence for an association of coxsackie virus infections during pregnancy and early childhood with development of islet autoantibodies in offspring of mothers or fathers with type 1 diabetes. J Autoimmun. 2001;17(4):333-340. doi:10.1006/jaut.2001.0550 11771958
144 Graves PM, Rotbart HA, Nix WA, et al. Prospective study of enteroviral infections and development of beta-cell autoimmunity. Diabetes Autoimmunity Study in the Young (DAISY). Diabetes Res Clin Pract. 2003;59(1):51-61. doi:10.1016/s0168-8227(02)00198-5 12482642
145 Laitinen OH, Honkanen H, Pakkanen O, et al. Coxsackievirus B1 is associated with induction of β-cell autoimmunity that portends type 1 diabetes. Diabetes. 2014;63(2):446-455. doi:10.2337/db13-0619 23974921
146 Cinek O, Stene LC, Kramna L, et al. Enterovirus RNA in longitudinal blood samples and risk of islet autoimmunity in children with a high genetic risk of type 1 diabetes: the MIDIA study. Diabetologia. 2014;57(10):2193-2200. doi:10.1007/s00125-014-3327-4 25047648
147 Hyöty H, Hiltunen M, Knip M, et al. A prospective study of the role of coxsackie B and other enterovirus infections in the pathogenesis of IDDM. Childhood Diabetes in Finland (DiMe) Study Group. Diabetes. 1995;44(6):652-657. doi:10.2337/diab.44.6.652 7789630
148 Tracy S, Drescher KM, Jackson JD, Kim K, Kono K. Enteroviruses, type 1 diabetes and hygiene: a complex relationship. Rev Med Virol. 2010;20(2):106-116. doi:10.1002/rmv.639 20049905
149 Dahlquist G, Ivarsson S, Lindberg B, Forsgren M. Maternal enteroviral infection during pregnancy as a risk factor for childhood IDDM. A population-based case-control study. Diabetes. 1995;44(4):408-413. doi:10.2337/diab.44.4.408 7698508
150 Dahlquist GG, Boman JE, Juto P. Enteroviral RNA and IgM antibodies in early pregnancy and risk for childhood-onset IDDM in offspring (Letter). Diabetes Care. 1999;22(2):364-365. doi:10.2337/diacare.22.2.364 10333962
151 Dahlquist GG, Forsberg J, Hagenfeldt L, Boman J, Juto P. Increased prevalence of enteroviral RNA in blood spots from newborn children who later developed type 1 diabetes: a population-based case-control study (Letter). Diabetes Care. 2004;27(1):285-286. doi:10.2337/diacare.27.1.285 14694014
152 Sadeharju K, Hämäläinen AM, Knip M, et al. Enterovirus infections as a risk factor for type I diabetes: virus analyses in a dietary intervention trial. Clin Exp Immunol. 2003;132(2):271-277. doi:10.1046/j.1365-2249.2003.02147.x 12699416
153 Viskari HR, Roivainen M, Reunanen A, et al. Maternal first-trimester enterovirus infection and future risk of type 1 diabetes in the exposed fetus. Diabetes. 2002;51(8):2568-2571. doi:10.2337/diabetes.51.8.2568 12145172
154 Viskari H, Knip M, Tauriainen S, et al. Maternal enterovirus infection as a risk factor for type 1 diabetes in the exposed offspring. Diabetes Care. 2012;35(6):1328-1332. doi:10.2337/dc11-2389 22432113
155 Gottesman BL, Yu J, Tanaka C, Longhurst CA, Kim JJ. Incidence of new-onset type 1 diabetes among US children during the COVID-19 global pandemic. JAMA Pediatr. 2022;176(4):414-415. doi:10.1001/jamapediatrics.2021.5801 35072727
156 Wolf RM, Noor N, Izquierdo R, et al. Increase in newly diagnosed type 1 diabetes in youth during the COVID-19 pandemic in the United States: a multi-center analysis. Pediatr Diabetes. 2022;23(4):433-438. doi:10.1111/pedi.13328 35218124
157 van der Heide V, Jangra S, Cohen P, et al. Limited extent and consequences of pancreatic SARS-CoV-2 infection. Cell Rep. 2022;38(11):110508. doi:10.1016/j.celrep.2022.110508 35247306
158 Kusmartseva I, Wu W, Syed F, et al. Expression of SARS-CoV-2 entry factors in the pancreas of normal organ donors and individuals with COVID-19. Cell Metab. 2020;32(6):1041-1051.e6 doi:10.1016/j.cmet.2020.11.005 33207244
159 Harding JL, Oviedo SA, Ali MK, et al. The bidirectional association between diabetes and long-COVID-19—a systematic review. Diabetes Res Clin Pract. 2022;195:110202. doi:10.1016/j.diabres.2022.110202 36496030
160 Barrett CE, Koyama AK, Alvarez P, et al. Risk for newly diagnosed diabetes >30 days after SARS-CoV-2 infection among persons aged <18 years — United States, March 1, 2020–June 28, 2021. MMWR Morb Mortal Wkly Rep. 2022;71(2):59-65. doi:10.15585/mmwr.mm7102e2 35025851
161 Pietropaolo M, Hotez P, Giannoukakis N. Incidence of an insulin-requiring hyperglycemic syndrome in SARS CoV-2-infected young individuals: is it type 1 diabetes? Diabetes. 2022;71(12):2656-2663. doi:10.2337/db21-0831 35293987
162 Kendall EK, Olaker VR, Kaelber DC, Xu R, Davis PB. Association of SARS-CoV-2 infection with new-onset type 1 diabetes among pediatric patients from 2020 to 2021. JAMA Netw Open. 2022;5(9):e2233014. doi:10.1001/jamanetworkopen.2022.33014 36149658
163 Qeadan F, Tingey B, Egbert J, et al. The associations between COVID-19 diagnosis, type 1 diabetes, and the risk of diabetic ketoacidosis: a nationwide cohort from the US using the Cerner Real-World Data. PLoS One. 2022;17(4):e0266809. doi:10.1371/journal.pone.0266809 35439266
164 McKeigue PM, McGurnaghan S, Blackbourn L, et al. Relation of incident type 1 diabetes to recent COVID-19 infection: cohort study using e-health record linkage in Scotland. Diabetes Care. 2022;46(5):921-928. doi:10.2337/dc22-0385
165 Noorzae R, Junker TG, Hviid AP, Wohlfahrt J, Olsen SF. Risk of type 1 diabetes in children is not increased after SARS-CoV-2 infection: a nationwide prospective study in Denmark. Diabetes Care. 2023;46(6):1261-1264. doi:10.2337/dc22-2351 37058353
166 Gulseth HL, Ruiz PLD, Størdal K, et al. SARS-CoV-2 infection and subsequent risk of type 1 diabetes in 1.2 million children. Abstract 233 presented at: 58th EASD Annual Meeting of the European Association for the Study of Diabetes; September 19–23 2022; Stockholm, Sweden. doi:10.1007/s00125-022-05755-w
167 Rewers M, Bonifacio E, Ewald D, et al. SARS-CoV-2 infections and presymptomatic type 1 diabetes autoimmunity in children and adolescents from Colorado, USA, and Bavaria, Germany. JAMA. 2022;328(12):1252-1255. doi:doi:10.1001/jama.2022.14092 35930271
168 Jääskeläinen AJ, Nurminen N, Kolehmainen P, et al. No association between Ljungan virus seropositivity and the beta-cell damaging process in the Finnish type 1 diabetes prediction and prevention study cohort. Pediatr Infect Dis J. 2019;38(3):314-316. doi:10.1097/inf.0000000000002201 30346370
169 Tapia G, Cinek O, Rasmussen T, Grinde B, Stene LC, Rønningen KS. Longitudinal study of parechovirus infection in infancy and risk of repeated positivity for multiple islet autoantibodies: the MIDIA study. Pediatr Diabetes. 2011;12(1):58-62. doi:10.1111/j.1399-5448.2010.00658.x 21226816
170 Tapia G, Bøås H, de Muinck EJ, et al. Saffold virus, a human cardiovirus, and risk of persistent islet autoantibodies in the longitudinal birth cohort study MIDIA. PLoS One. 2015;10(8):e0136849. doi:10.1371/journal.pone.0136849 26317929
171 Kondrashova A, Nurminen N, Patrikainen M, et al. Influenza A virus antibodies show no association with pancreatic islet autoantibodies in children genetically predisposed to type 1 diabetes. Diabetologia. 2015;58(11):2592-2595. doi:10.1007/s00125-015-3723-4 26253765
172 Ruiz PLD, Tapia G, Bakken IJ, et al. Pandemic influenza and subsequent risk of type 1 diabetes: a nationwide cohort study. Diabetologia. 2018;61(9):1996-2004. doi:10.1007/s00125-018-4662-7 29934759
173 Onodera T, Jenson AB, Yoon JW, Notkins AL. Virus-induced diabetes mellitus: reovirus infection of pancreatic beta cells in mice. Science. 1978;201(4355):529-531. doi:10.1126/science.208156 208156
174 Honeyman M. How robust is the evidence for viruses in the induction of type 1 diabetes? Curr Opin Immunol. 2005;17(6):616-623. doi:10.1016/j.coi.2005.09.007 16216484
175 Mäkelä M, Vaarala O, Hermann R, et al. Enteral virus infections in early childhood and an enhanced type 1 diabetes-associated antibody response to dietary insulin. J Autoimmun. 2006;27(1):54-61. doi:10.1016/j.jaut.2006.04.003 16757149
176 Honeyman MC, Coulson BS, Stone NL, et al. Association between rotavirus infection and pancreatic islet autoimmunity in children at risk of developing type 1 diabetes. Diabetes. 2000;49(8):1319-1324. doi:10.2337/diabetes.49.8.1319 10923632
177 Blomqvist M, Juhela S, Erkkilä S, et al. Rotavirus infections and development of diabetes-associated autoantibodies during the first 2 years of life. Clin Exp Immunol. 2002;128(3):511-515. doi:10.1046/j.1365-2249.2002.01842.x 12067306
178 Pak CY, Eun HM, McArthur RG, Yoon JW. Association of cytomegalovirus infection with autoimmune type 1 diabetes. Lancet. 1988;2(8601):1-4. doi:10.1016/s0140-6736(88)92941-8 2898620
179 Ward KP, Galloway WH, Auchterlonie IA. Congenital cytomegalovirus infection and diabetes. Lancet. 1979;1(8114):497. doi:10.1016/s0140-6736(79)90853-5
180 Nicoletti F, Scalia G, Lunetta M, et al. Correlation between islet cell antibodies and anti-cytomegalovirus IgM and IgG antibodies in healthy first-degree relatives of type 1 (insulin-dependent) diabetic patients. Clin Immunol Immunopathol. 1990;55(1):139-147. doi:10.1016/0090-1229(90)90075-2 2155076
181 Banatvala JE, Bryant J, Schernthaner G, et al. Coxsackie B, mumps, rubella, and cytomegalovirus specific IgM responses in patients with juvenile-onset insulin-dependent diabetes mellitus in Britain, Austria, and Australia. Lancet. 1985;1(8443):1409-1412. doi:10.1016/s0140-6736(85)91843-4 2861361
182 Hiltunen M, Hyöty H, Karjalainen J, et al. Serological evaluation of the role of cytomegalovirus in the pathogenesis of IDDM: a prospective study Diabetologia. 1995;38(6):705-710. doi:10.1007/BF00401843 7672493
183 Ivarsson SA, Lindberg B, Nilsson KO, Ahlfors K, Svanberg L. The prevalence of type 1 diabetes mellitus at follow-up of Swedish infants congenitally infected with cytomegalovirus. Diabet Med. 1993;10(6):521-523. doi:10.1111/j.1464-5491.1993.tb00113.x 8395988
184 Aarnisalo J, Veijola R, Vainionpää R, Simell O, Knip M, Ilonen J. Cytomegalovirus infection in early infancy: risk of induction and progression of autoimmunity associated with type 1 diabetes. Diabetologia. 2008;51(5):769-772. doi:10.1007/s00125-008-0945-8 18278478
185 Ekman I, Vuorinen T, Knip M, et al. Early childhood CMV infection may decelerate the progression to clinical type 1 diabetes. Pediatr Diabetes. 2019;20(1):73-77. doi:10.1111/pedi.12788 30338642
186 Lee HS, Briese T, Winkler C, et al. Next-generation sequencing for viruses in children with rapid-onset type 1 diabetes. Diabetologia. 2013;56(8):1705-1711. doi:10.1007/s00125-013-2924-y 23657799
187 Faulkner CL, Luo YX, Isaacs S, Rawlinson WD, Craig ME, Kim KW. The virome in early life and childhood and development of islet autoimmunity and type 1 diabetes: a systematic review and meta-analysis of observational studies. Rev Med Virol. 2021;31(5):1-14. doi:10.1002/rmv.2209
188 TEDDY Study Group. The Environmental Determinants of Diabetes in the Young (TEDDY) Study. Ann N Y Acad Sci. 2008;1150(1):1-13. doi:10.1196/annals.1447.062
189 Vatanen T, Franzosa EA, Schwager R, et al. The human gut microbiome in early-onset type 1 diabetes from the TEDDY study. Nature. 2018;562(7728):589-594. doi:10.1038/s41586-018-0620-2 30356183
190 Stewart CJ, Ajami NJ, O’Brien JL, et al. Temporal development of the gut microbiome in early childhood from the TEDDY study. Nature. 2018;562(7728):583-588. doi:10.1038/s41586-018-0617-x 30356187
191 Auchtung TA, Stewart CJ, Smith DP, et al. Temporal changes in gastrointestinal fungi and the risk of autoimmunity during early childhood: the TEDDY study. Nat Commun. 2022;13(1):3151. doi:10.1038/s41467-022-30686-w 35672407
192 Bach JF. The hygiene hypothesis in autoimmunity: the role of pathogens and commensals. Nat Rev Immunol. 2018;18(2):105-120. doi:10.1038/nri.2017.111 29034905
193 Gale EA. A missing link in the hygiene hypothesis? Diabetologia. 2002;45(4):588-594. doi:10.1007/s00125-002-0801-1 12032638
194 Haahtela T. A biodiversity hypothesis. Allergy. 2019;74(8):1445-1456. doi:10.1111/all.13763 30835837
195 Roslund MI, Parajuli A, Hui N, et al. A placebo-controlled double-blinded test of the biodiversity hypothesis of immune-mediated diseases: environmental microbial diversity elicits changes in cytokines and increase in T regulatory cells in young children. Ecotoxicol Environ Saf. 2022;242:113900. doi:10.1016/j.ecoenv.2022.113900 35930838
196 Cardwell CR, Stene LC, Joner G, et al. Birth order and childhood type 1 diabetes risk: a pooled analysis of 31 observational studies. Int J Epidemiol. 2011;40(2):363-374. doi:10.1093/ije/dyq207 21149280
197 Borchers AT, Uibo R, Gershwin ME. The geoepidemiology of type 1 diabetes. Autoimmun Rev. 2010;9(5):A355-A365. doi:10.1016/j.autrev.2009.12.003 19969107
198 Samuelsson U, Westerberg L, Aakesson K, et al. Geographical variation in the incidence of type 1 diabetes in the Nordic countries: a study within NordicDiabKids. Pediatr Diabetes. 2020;21(2):259-265. doi:10.1111/pedi.12943 31702838
199 Rytkönen M, Ranta J, Tuomilehto J, Karvonen M, SPAT Study Group, Finnish Childhood Diabetes Registry Group. Bayesian analysis of geographical variation in the incidence of type I diabetes in Finland. Diabetologia. 2001;44(Suppl 3):B37-B44. doi:10.1007/Pl00002952 11724415
200 Rytkönen M, Moltchanova E, Ranta J, Taskinen O, Tuomilehto J, Karvonen M. The incidence of type 1 diabetes among children in Finland—rural-urban difference. Health Place. 2003;9(4):315-325. doi:10.1016/s1353-8292(02)00064-3 14499216
201 Stene LC, Barriga K, Norris JM, et al. Symptoms of common maternal infections in pregnancy and risk of islet autoimmunity in early childhood. Diabetes Care. 2003;26(11):3136-3141. doi:10.2337/diacare.26.11.3136 14578251
202 Bruno G, Spadea T, Picariello R, et al. Early life socioeconomic indicators and risk of type 1 diabetes in children and young adults. J Pediatr. 2013;162(3):600-605. doi:10.1016/j.jpeds.2012.09.010 23084710
203 von Mutius E. The “hygiene hypothesis” and the lessons learnt from farm studies. Front Immunol. 2021;12:635522. doi:10.3389/fimmu.2021.635522 33868259
204 Radon K, Windstetter D, Solfrank S, et al. Exposure to farming environments in early life and type 1 diabetes: a case-control study. Diabetes. 2005;54(11):3212-3216. doi:10.2337/diabetes.54.11.3212 16249447
205 Virtanen SM, Takkinen HM, Nwaru BI, et al. Microbial exposure in infancy and subsequent appearance of type 1 diabetes mellitus-associated autoantibodies: a cohort study. JAMA Pediatr. 2014;168(8):755-763. doi:10.1001/jamapediatrics.2014.296 24957949
206 Lopez-Doriga Ruiz P, Tapia G, Bakken IJ, et al. Parental education and occupation in relation to risk of childhood type 1 diabetes: nationwide cohort study. medRxiv. 2022:2022.07.26.22277835. doi:10.1101/2022.07.26.22277835
207 Bager P, Vinkel Hansen A, Wohlfahrt J, Melbye M. Helminth infection does not reduce risk for chronic inflammatory disease in a population-based cohort study. Gastroenterology. 2012;142(1):55-62. doi:10.1053/j.gastro.2011.09.046 21983081
208 Bøås H, Tapia G, Sødahl JA, Rasmussen T, Rønningen KS. Enterobius vermicularis and risk factors in healthy Norwegian children. Pediatr Infect Dis J. 2012;31(9):927-930. doi:10.1097/INF.0b013e318258cdb5 22531241
209 Kemppainen KM, Vehik K, Lynch KF, et al. Association between early-life antibiotic use and the risk of islet or celiac disease autoimmunity. JAMA Pediatr. 2017;171(12):1217-1225. doi:10.1001/jamapediatrics.2017.2905 29052687
210 Kilkkinen A, Virtanen SM, Klaukka T, et al. Use of antimicrobials and risk of type 1 diabetes in a population-based mother-child cohort. Diabetologia. 2006;49(1):66-70. doi:10.1007/s00125-005-0078-2 16344923
211 Hviid A, Svanström H. Antibiotic use and type 1 diabetes in childhood. Am J Epidemiol. 2009;169(9):1079-1084. doi:10.1093/aje/kwp038 19318617
212 Clausen TD, Bergholt T, Bouaziz O, et al. Broad-spectrum antibiotic treatment and subsequent childhood type 1 diabetes: a nationwide Danish cohort study. PLoS One. 2016;11(8):e0161654. doi:10.1371/journal.pone.0161654 27560963
213 Mikkelsen KH, Knop FK, Vilsbøll T, Frost M, Hallas J, Pottegård A. Use of antibiotics in childhood and risk of type 1 diabetes: a population-based case-control study. Diabet Med. 2017;34(2):272-277. doi:10.1111/dme.13262 27646695
214 Haupt-Jørgensen M, Morgen CS, Jess T, et al. Maternal antibiotic use during pregnancy and type 1 diabetes in children-a national prospective cohort study. Diabetes Care. 2018;41(12):e155-e157. doi:10.2337/dc18-1764 30327353
215 Gamble DR. The epidemiology of insulin dependent diabetes, with particular reference to the relationship of virus infection to its etiology. Epidemiol Rev. 1980;2(1):49-70. doi:10.1093/oxfordjournals.epirev.a036226 7000538
216 Athreya BH, Coriell LL, Charney J. Poliomyelitis antibodies in human colostrum and milk. J Pediatr. 1964;64(1):79-82. doi:10.1016/s0022-3476(64)80320-6 14100104
217 Viskari H, Ludvigsson J, Uibo R, et al. Relationship between the incidence of type 1 diabetes and maternal enterovirus antibodies: time trends and geographical variation. Diabetologia. 2005;48(7):1280-1287. doi:10.1007/s00125-005-1780-9 15902401
218 Larsson PG, Lakshmikanth T, Svedin E, King C, Flodström-Tullberg M. Previous maternal infection protects offspring from enterovirus infection and prevents experimental diabetes development in mice. Diabetologia. 2013;56(4):867-874. doi:10.1007/s00125-013-2834-z 23344730
219 Jefferson T, Demicheli V. No evidence that vaccines cause insulin dependent diabetes mellitus. J Epidemiol Community Health. 1998;52(10):674-675. doi:10.1136/jech.52.10.674 10023469
220 Graves PM, Barriga KJ, Norris JM, et al. Lack of association between early childhood immunizations and beta-cell autoimmunity. Diabetes Care. 1999;22(10):1694-1697. doi:10.2337/diacare.22.10.1694 10526737
221 Hummel M, Füchtenbusch M, Schenker M, Ziegler AG. No major association of breast-feeding, vaccinations, and childhood viral diseases with early islet autoimmunity in the German BABYDIAB Study. Diabetes Care. 2000;23(7):969-974. doi:10.2337/diacare.23.7.969 10895848
222 Offit PA, Hackett CJ. Addressing parents’ concerns: do vaccines cause allergic or autoimmune diseases? Pediatrics. 2003;111(3):653-659. doi:10.1542/peds.111.3.653 12612250
223 Morgan E, Halliday SR, Campbell GR, Cardwell CR, Patterson CC. Vaccinations and childhood type 1 diabetes mellitus: a meta-analysis of observational studies. Diabetologia. 2016;59(2):237-243. doi:10.1007/s00125-015-3800-8 26564178
224 Glanz JM, Clarke CL, Daley MF, et al. The childhood vaccination schedule and the lack of association with type 1 diabetes. Pediatrics. 2021;148(6):e2021051910. doi:10.1542/peds.2021-051910 34851413
225 Beyerlein A, Strobl AN, Winkler C, et al. Vaccinations in early life are not associated with development of islet autoimmunity in type 1 diabetes high-risk children: Results from prospective cohort data. Vaccine. 2017;35(14):1735-1741. doi:10.1016/j.vaccine.2017.02.049 28268073
226 Salo EP. BCG in Finland: changing from a universal to a selected programme. Euro Surveill. 2006;11(3):18-20. doi:10.2807/esm.11.03.00607-en 16567879
227 Parent ME, Siemiatycki J, Menzies R, Fritschi L, Colle E. Bacille Calmette-Guérin vaccination and incidence of IDDM in Montreal, Canada. Diabetes Care. 1997;20(5):767-772. doi:10.2337/diacare.20.5.767 9135940
228 Dahlquist G, Gothefors L. The cumulative incidence of childhood diabetes mellitus in Sweden unaffected by BCG-vaccination. Diabetologia. 1995;38(7):873-874. doi:10.1007/bf03035306 7556994
229 Huppmann M, Baumgarten A, Ziegler AG, Bonifacio E. Neonatal Bacille Calmette-Guerin vaccination and type 1 diabetes. Diabetes Care. 2005;28(5):1204-1206. doi:10.2337/diacare.28.5.1204 15855590
230 Rousseau MC, El-Zein M, Conus F, Legault L, Parent ME. Bacillus Calmette-Guérin (BCG) vaccination in infancy and risk of childhood diabetes. Paediatr Perinat Epidemiol. 2016;30(2):141-148. doi:10.1111/ppe.12263 26584963
231 Elliott JF, Marlin KL, Couch RM. Effect of bacille Calmette-Guérin vaccination on C-peptide secretion in children newly diagnosed with IDDM. Diabetes Care. 1998;21(10):1691-1693. doi:10.2337/diacare.21.10.1691 9773732
232 Allen HF, Klingensmith GJ, Jensen P, Simoes E, Hayward A, Chase HP. Effect of Bacillus Calmette-Guerin vaccination on new-onset type 1 diabetes. A randomized clinical study. Diabetes Care. 1999;22(10):1703-1707. doi:10.2337/diacare.22.10.1703 10526739
233 Viskari H, Oikarinen S, Hoppu S, et al. Live attenuated enterovirus vaccine (OPV) is not associated with islet autoimmunity in children with genetic susceptibility to type 1 diabetes: prospective cohort study. Diabetologia. 2018;61(1):203-209. doi:10.1007/s00125-017-4410-4 28866779
234 Rogers MAM, Basu T, Kim C. Lower incidence rate of type 1 diabetes after receipt of the rotavirus vaccine in the United States, 2001–2017. Sci Rep. 2019;9(1):7727. doi:10.1038/s41598-019-44193-4 31197227
235 Perrett KP, Jachno K, Nolan TM, Harrison LC. Association of rotavirus vaccination with the incidence of type 1 diabetes in children. JAMA Pediatr. 2019;173(3):280-282. doi:10.1001/jamapediatrics.2018.4578 30667473
236 Vaarala O, Jokinen J, Lahdenkari M, Leino T. Rotavirus vaccination and the risk of celiac disease or type 1 diabetes in Finnish children at early life. Pediatr Infect Dis J. 2017;36(7):674-675. doi:10.1097/inf.0000000000001600 28399059
237 Hemming-Harlo M, Lähdeaho ML, Mäki M, Vesikari T. Rotavirus vaccination does not increase type 1 diabetes and may decrease celiac disease in children and adolescents. Pediatr Infect Dis J. 2019;38(5):539-541. doi:10.1097/inf.0000000000002281 30986791
238 Glanz JM, Clarke CL, Xu S, et al. Association between rotavirus vaccination and type 1 diabetes in children. JAMA Pediatr. 2020;174(5):455-462. doi:10.1001/jamapediatrics.2019.6324 32150236
239 Inns T, Fleming KM, Iturriza-Gomara M, Hungerford D. Paediatric rotavirus vaccination, coeliac disease and type 1 diabetes in children: a population-based cohort study. BMC Med. 2021;19(1):147. doi:10.1186/s12916-021-02017-1 34183004
240 Burke RM, Tate JE, Jiang B, Parashar UD. Rotavirus and type 1 diabetes—is there a connection? A synthesis of the evidence. J Infect Dis. 2020;222(7):1076-1083. doi:10.1093/infdis/jiaa168 32249284
241 Ruiz PLD, Stene LC, Gulseth HL, et al. Pandemic influenza A H1N1 vaccination and subsequent risk of type 1 diabetes in Norway. Epidemiology. 2018;29(1):e6-e8. doi:10.1097/ede.0000000000000748 28885449
242 Elding Larsson H, Lynch KF, Lönnrot M, et al. Pandemrix(R) vaccination is not associated with increased risk of islet autoimmunity or type 1 diabetes in the TEDDY study children. Diabetologia. 2018;61(1):193-202. doi:10.1007/s00125-017-4448-3 28990147
243 Tapia G, Lopez-Doriga Ruiz P, Gunnes N, et al. Incidence of type 1 diabetes after SARS-CoV-2 infection in 123 382 children. Abstract presented at: European Diabetes Epidemiology Group (EDEG) 56th Annual Meeting; April 2–5 2022; Crete, Greece.
244 Brown CT, Davis-Richardson AG, Giongo A, et al. Gut microbiome metagenomics analysis suggests a functional model for the development of autoimmunity for type 1 diabetes. PLoS One. 2011;6(10):e25792. doi:10.1371/journal.pone.0025792 22043294
245 de Goffau MC, Luopajärvi K, Knip M, et al. Fecal microbiota composition differs between children with beta-cell autoimmunity and those without. Diabetes. 2013;62(4):1238-1244. doi:10.2337/db12-0526 23274889
246 Murri M, Leiva I, Gomez-Zumaquero JM, et al. Gut microbiota in children with type 1 diabetes differs from that in healthy children: a case-control study. BMC Med. 2013;11:46. doi:10.1186/1741-7015-11-46 23433344
247 Endesfelder D, zu Castell W, Ardissone A, et al. Compromised gut microbiota networks in children with anti-islet cell autoimmunity. Diabetes. 2014;63(6):2006-2014. doi:10.2337/db13-1676 24608442
248 Giongo A, Gano KA, Crabb DB, et al. Toward defining the autoimmune microbiome for type 1 diabetes. ISME J. 2011;5(1):82-91. doi:10.1038/ismej.2010.92 20613793
249 Gülden E, Wong FS, Wen L. The gut microbiota and type 1 diabetes. Clin Immunol. 2015;159(2):143-153. doi:10.1016/j.clim.2015.05.013 26051037
250 Kostic AD, Gevers D, Siljander H, et al. The dynamics of the human infant gut microbiome in development and in progression toward type 1 diabetes. Cell Host Microbe. 2015;17(2):260-273. doi:10.1016/j.chom.2015.01.001 25662751
251 Siljander H, Honkanen J, Knip M. Microbiome and type 1 diabetes. EBioMedicine. 2019;46:512-521. doi:10.1016/j.ebiom.2019.06.031 31257149
252 Uusitalo U, Liu X, Yang J, et al. Association of early exposure of probiotics and islet autoimmunity in the TEDDY study. JAMA Pediatr. 2016;170(1):20-28. doi:10.1001/jamapediatrics.2015.2757 26552054
253 Ziegler AG, Arnolds S, Kölln A, et al. Supplementation with Bifidobacterium longum subspecies infantis EVC001 for mitigation of type 1 diabetes autoimmunity: the GPPAD-SINT1A randomised controlled trial protocol. BMJ Open. 2021;11(11):e052449. doi: PMC8578987,10.1136/bmjopen-2021-052449
254 Erkkola M, Nwaru BI, Viljakainen HT. Maternal vitamin D during pregnancy and its relation to immune-mediated diseases in the offspring. Vitam Horm. 2011;86:239-260. doi:10.1016/b978-0-12-386960-9.00010-1 21419274
255 Laron Z, Lewy H, Wilderman I, et al. Seasonality of month of birth of children and adolescents with type 1 diabetes mellitus in homogenous and heterogeneous populations. Isr Med Assoc J. 2005;7(6):381-384.15984382
256 Muntoni S, Karvonen M, Muntoni S, Tuomilehto J. Seasonality of birth in patients with type 1 diabetes. Lancet. 2002;359(9313):1246. doi:10.1016/s0140-6736(02)08227-2
257 Dong JY, Zhang WG, Chen JJ, Zhang ZL, Han SF, Qin LQ. Vitamin D intake and risk of type 1 diabetes: a meta-analysis of observational studies. Nutrients. 2013;5(9):3551-3562. doi:10.3390/nu5093551 24036529
258 Sørensen IM, Joner G, Jenum PA, Eskild A, Torjesen PA, Stene LC. Maternal serum levels of 25-hydroxy-vitamin D during pregnancy and risk of type 1 diabetes in the offspring. Diabetes. 2012;61(1):175-178. doi:10.2337/db11-0875 22124461
259 Miettinen ME, Reinert L, Kinnunen L, et al. Serum 25-hydroxyvitamin D level during early pregnancy and type 1 diabetes risk in the offspring. Diabetologia. 2012;55(5):1291-1294. doi:10.1007/s00125-012-2458-8 22270224
260 Thorsen SU, Mårild K, Olsen SF, et al. Lack of association between maternal or neonatal vitamin D status and risk of childhood type 1 diabetes: a Scandinavian case-cohort study. Am J Epidemiol. 2018;187(6):1174-1181. doi:10.1093/aje/kwx361 29186303
261 Mäkinen M, Löyttyniemi E, Koskinen M, et al. Serum 25-hydroxyvitamin D concentrations at birth in children screened for HLA-DQB1 conferred risk for type 1 diabetes. J Clin Endocrinol Metab. 2019;104(6):2277-2285. doi:10.1210/jc.2018-02094 30657906
262 Jacobsen R, Thorsen SU, Cohen AS, et al. Neonatal vitamin D status is not associated with later risk of type 1 diabetes: results from two large Danish population-based studies. Diabetologia. 2016;59(9):1871-1881. doi:10.1007/s00125-016-4002-8 27241183
263 Antvorskov JC, Halldorsson TI, Josefsen K, et al. Association between maternal gluten intake and type 1 diabetes in offspring: national prospective cohort study in Denmark. BMJ. 2018;362:k3547. doi:10.1136/bmj.k3547 30232082
264 Lund-Blix NA, Tapia G, Mårild K, et al. Maternal and child gluten intake and association with type 1 diabetes: the Norwegian Mother and Child Cohort Study. PLoS Med. 2020;17(3):e1003032. doi:10.1371/journal.pmed.1003032 32119659
265 Johnson RK, Tamura R, Frank N, et al. Maternal food consumption during late pregnancy and offspring risk of islet autoimmunity and type 1 diabetes. Diabetologia. 2021;64(7):1604-1612. doi:10.1007/s00125-021-05446-y 33783586
266 Størdal K, McArdle HJ, Hayes H, et al. Prenatal iron exposure and childhood type 1 diabetes. Sci Rep. 2018;8(1):9067. doi:10.1038/s41598-018-27391-4 29899542
267 Mattila M, Hakola L, Niinistö S, et al. Maternal vitamin C and iron intake during pregnancy and the risk of islet autoimmunity and type 1 diabetes in children: a birth cohort study. Nutrients. 2021;13(3):928. doi:10.3390/nu13030928 33805588
268 Uusitalo L, Kenward MG, Virtanen SM, et al. Intake of antioxidant vitamins and trace elements during pregnancy and risk of advanced beta cell autoimmunity in the child. Am J Clin Nutr. 2008;88(2):458-464. doi:10.1093/ajcn/88.2.458 18689383
269 Silvis K, Aronsson CA, Liu X, et al. Maternal dietary supplement use and development of islet autoimmunity in the offspring: TEDDY study. Pediatr Diabetes. 2019;20(1):86-92. doi:10.1111/pedi.12794 30411443
270 Sørensen IM, Joner G, Jenum PA, Eskild A, Stene LC. Serum long chain n-3 fatty acids (EPA and DHA) in the pregnant mother are independent of risk of type 1 diabetes in the offspring. Diabetes Metab Res Rev. 2012;28(5):431-438. doi:10.1002/dmrr.2293 22396195
271 Cardwell CR, Stene LC, Ludvigsson J, et al. Breast-feeding and childhood-onset type 1 diabetes: a pooled analysis of individual participant data from 43 observational studies. Diabetes Care. 2012;35(11):2215-2225. doi:10.2337/dc12-0438 22837371
272 Norris JM, Beaty B, Klingensmith G, et al. Lack of association between early exposure to cow’s milk protein and beta-cell autoimmunity. Diabetes Autoimmunity Study in the Young (DAISY). JAMA. 1996;276(8):609-614. doi:10.1001/jama.290.13.1713 8773632
273 Norris JM, Barriga K, Klingensmith G, et al. Timing of initial cereal exposure in infancy and risk of islet autoimmunity. JAMA. 2003;290(13):1713-1720. doi:10.1001/jama.290.13.1713 14519705
274 Frederiksen B, Kroehl M, Lamb MM, et al. Infant exposures and development of type 1 diabetes mellitus: the Diabetes Autoimmunity Study in the Young (DAISY). JAMA Pediatr. 2013;167(9):808-815. doi:10.1001/jamapediatrics.2013.317 23836309
275 Couper JJ, Steele C, Beresford S, et al. Lack of association between duration of breast-feeding or introduction of cow’s milk and development of islet autoimmunity. Diabetes. 1999;48(11):2145-2149. doi:10.2337/diabetes.48.11.2145 10535447
276 Ziegler AG, Schmid S, Huber D, Hummel M, Bonifacio E. Early infant feeding and risk of developing type 1 diabetes-associated autoantibodies. JAMA. 2003;290(13):1721-1728. doi:10.1001/jama.290.13.1721 14519706
277 Virtanen SM, Kenward MG, Erkkola M, et al. Age at introduction of new foods and advanced beta cell autoimmunity in young children with HLA-conferred susceptibility to type 1 diabetes. Diabetologia. 2006;49(7):1512-1521. doi:10.1007/s00125-006-0236-1 16596359
278 Virtanen SM, Takkinen HM, Nevalainen J, et al. Early introduction of root vegetables in infancy associated with advanced ß-cell autoimmunity in young children with human leukocyte antigen-conferred susceptibility to type 1 diabetes. Diabet Med. 2011;28(8):965-971. doi:10.1111/j.1464-5491.2011.03294.x 21418094
279 Hakola L, Takkinen HM, Niinistö S, et al. Infant feeding in relation to the risk of advanced islet autoimmunity and type 1 diabetes in children with increased genetic susceptibility: a cohort study. Am J Epidemiol. 2018;187(1):34-44. doi:10.1093/aje/kwx191 29309515
280 Lund-Blix NA, Stene LC, Rasmussen T, Torjesen PA, Andersen LF, Rønningen KS. Infant feeding in relation to islet autoimmunity and type 1 diabetes in genetically susceptible children: the MIDIA Study. Diabetes Care. 2015;38(2):257-263. doi:10.2337/dc14-1130 25422170
281 Uusitalo U, Lee HS, Andrén Aronsson C, et al. Early infant diet and islet autoimmunity in the TEDDY study. Diabetes Care. 2018;41(3):522-530. doi:10.2337/dc17-1983 29343517
282 Hummel S, Weiß A, Bonifacio E, et al. Associations of breastfeeding with childhood autoimmunity, allergies, and overweight: The Environmental Determinants of Diabetes in the Young (TEDDY) study. Am J Clin Nutr. 2021;114(1):134-142. doi:10.1093/ajcn/nqab065 33831944
283 Lund-Blix NA, Dydensborg Sander S, Størdal K, et al. Infant feeding and risk of type 1 diabetes in two large Scandinavian birth cohorts. Diabetes Care. 2017;40(7):920-927. doi:10.2337/dc17-0016 28487451
284 Elliott RB, Martin JM. Dietary protein: a trigger of insulin-dependent diabetes in the BB rat? Diabetologia. 1984;26(4):297-299. doi:10.1007/bf00283653 6376238
285 Martin JM, Trink B, Daneman D, Dosch HM, Robinson B. Milk proteins in the etiology of insulin-dependent diabetes mellitus (IDDM). Ann Med. 1991;23(4):447-452. doi:10.3109/07853899109148088 1718325
286 Savilahti E, Saarinen KM. Early infant feeding and type 1 diabetes. Eur J Nutr. 2009;48(4):243-249. doi:10.1007/s00394-009-0008-z 19263185
287 Knip M, Åkerblom HK, Becker D, et al. Hydrolyzed infant formula and early b-cell autoimmunity: a randomized clinical trial. JAMA. 2014;311(22):2279-2287. doi:10.1001/jama.2014.5610 24915259
288 Knip M, Åkerblom HK, Al Taji E, et al. Effect of hydrolyzed infant formula vs conventional formula on risk of type 1 diabetes: the TRIGR randomized clinical trial. JAMA. 2018;319(1):38-48. doi:10.1001/jama.2017.19826 29297078
289 Hummel S, Beyerlein A, Tamura R, et al. First infant formula type and risk of islet autoimmunity in The Environmental Determinants of Diabetes in the Young (TEDDY) study. Diabetes Care. 2017;40(3):398-404. doi:10.2337/dc16-1624 28096222
290 Virtanen SM, Nevalainen J, Kronberg-Kippilä C, et al. Food consumption and advanced beta cell autoimmunity in young children with HLA-conferred susceptibility to type 1 diabetes: a nested case-control design. Am J Clin Nutr. 2012;95(2):471-478. doi:10.3945/ajcn.111.018879 22237062
291 Virtanen SM, Hyppönen E, Läärä E, et al. Cow’s milk consumption, disease-associated autoantibodies and type 1 diabetes mellitus: a follow-up study in siblings of diabetic children. Childhood Diabetes in Finland Study Group. Diabet Med. 1998;15(9):730-738. doi:10.1002/(sici)1096-9136(199809)15:9<730::Aid-dia646>3.0.Co;2-c 9737801
292 Virtanen SM, Läärä E, Hyppönen E, et al. Cow’s milk consumption, HLA-DQB1 genotype, and type 1 diabetes: a nested case-control study of siblings of children with diabetes. Childhood Diabetes in Finland Study Group. Diabetes. 2000;49(6):912-917. doi:10.2337/diabetes.49.6.912 10866042
293 Rosenbauer J, Herzig P, Giani G. Early infant feeding and risk of type 1 diabetes mellitus—a nationwide population-based case-control study in pre-school children. Diabetes Metab Res Rev. 2008;24(3):211-222. doi:10.1002/dmrr.791 17968982
294 Lamb MM, Miller M, Seifert JA, et al. The effect of childhood cow’s milk intake and HLA-DR genotype on risk of islet autoimmunity and type 1 diabetes: the Diabetes Autoimmunity Study in the Young. Pediatr Diabetes. 2015;16(1):31-38. doi:10.1111/pedi.12115 24444005
295 Niinistö S, Takkinen HM, Erlund I, et al. Fatty acid status in infancy is associated with the risk of type 1 diabetes-associated autoimmunity. Diabetologia. 2017;60(7):1223-1233. doi:10.1007/s00125-017-4280-9 28474159
296 Crowe FL, Skeaff CM, Green TJ, Gray AR. Serum fatty acids as biomarkers of fat intake predict serum cholesterol concentrations in a population-based survey of New Zealand adolescents and adults. Am J Clin Nutr. 2006;83(4):887-894. doi:10.1093/ajcn/83.4.887 16600943
297 Wolk A, Furuheim M, Vessby B. Fatty acid composition of adipose tissue and serum lipids are valid biological markers of dairy fat intake in men. J Nutr. 2001;131(3):828-833. doi:10.1093/jn/131.3.828 11238766
298 Hummel M, Bonifacio E, Naserke HE, Ziegler AG. Elimination of dietary gluten does not reduce titers of type 1 diabetes-associated autoantibodies in high-risk subjects. Diabetes Care. 2002;25(7):1111-1116. doi:10.2337/diacare.25.7.1111 12087006
299 Pastore MR, Bazzigaluppi E, Belloni C, Arcovio C, Bonifacio E, Bosi E. Six months of gluten-free diet do not influence autoantibody titers, but improve insulin secretion in subjects at high risk for type 1 diabetes. J Clin Endocrinol Metab. 2003;88(1):162-165. doi:10.1210/jc.2002-021177 12519846
300 Hummel S, Pflüger M, Hummel M, Bonifacio E, Ziegler AG. Primary dietary intervention study to reduce the risk of islet autoimmunity in children at increased risk for type 1 diabetes: the BABYDIET study. Diabetes Care. 2011;34(6):1301-1305. doi:10.2337/dc10-2456 21515839
301 Beyerlein A, Chmiel R, Hummel S, Winkler C, Bonifacio E, Ziegler AG. Timing of gluten introduction and islet autoimmunity in young children: updated results from the BABYDIET study. Diabetes Care. 2014;37(9):e194-e195. doi:10.2337/dc14-1208 25147260
302 Chmiel R, Beyerlein A, Knopff A, Hummel S, Ziegler AG, Winkler C. Early infant feeding and risk of developing islet autoimmunity and type 1 diabetes. Acta Diabetol. 2015;52(3):621-624. doi:10.1007/s00592-014-0628-5 25038720
303 Hakola L, Miettinen ME, Syrjälä E, et al. Association of cereal, gluten, and dietary fiber intake with islet autoimmunity and type 1 diabetes. JAMA Pediatr. 2019;173(10):953-960. doi:10.1001/jamapediatrics.2019.2564 31403683
304 Lund-Blix NA, Dong F, Mårild K, et al. Gluten intake and risk of islet autoimmunity and progression to type 1 diabetes in children at increased risk of the disease: the Diabetes Autoimmunity Study in the Young (DAISY). Diabetes Care. 2019;42(5):789-796. doi:10.2337/dc18-2315 30796108
305 Hyppönen E, Läärä E, Reunanen A, Järvelin MR, Virtanen SM. Intake of vitamin D and risk of type 1 diabetes: a birth-cohort study. Lancet. 2001;358(9292):1500-1503. doi:10.1016/s0140-6736(01)06580-1 11705562
306 Zipitis CS, Akobeng AK. Vitamin D supplementation in early childhood and risk of type 1 diabetes: a systematic review and meta-analysis. Arch Dis Child. 2008;93(6):512-517. doi:10.1136/adc.2007.128579 18339654
307 Simpson M, Brady H, Yin X, et al. No association of vitamin D intake or 25-hydroxyvitamin D levels in childhood with risk of islet autoimmunity and type 1 diabetes: the Diabetes Autoimmunity Study in the Young (DAISY). Diabetologia. 2011;54(11):2779-2788. doi:10.1007/s00125-011-2278-2 21858504
308 Mäkinen M, Mykkänen J, Koskinen M, et al. Serum 25-hydroxyvitamin D concentrations in children progressing to autoimmunity and clinical type 1 diabetes. J Clin Endocrinol Metab. 2016;101(2):723-729. doi:10.1210/jc.2015-3504 26695863
309 Norris JM, Lee HS, Frederiksen B, et al. Plasma 25-hydroxyvitamin D concentration and risk of islet autoimmunity. Diabetes. 2018;67(1):146-154. doi:10.2337/db17-0802 29061729
310 Miettinen ME, Niinistö S, Erlund I, et al. Serum 25-hydroxyvitamin D concentration in childhood and risk of islet autoimmunity and type 1 diabetes: the TRIGR nested case-control ancillary study. Diabetologia. 2020;63(4):780-787. doi:10.1007/s00125-019-05077-4 31912198
311 Gorham ED, Garland CF, Burgi AA, et al. Lower prediagnostic serum 25-hydroxyvitamin D concentration is associated with higher risk of insulin-requiring diabetes: a nested case-control study. Diabetologia. 2012;55(12):3224-3227. doi:10.1007/s00125-012-2709-8 22955995
312 Munger KL, Levin LI, Massa J, Horst R, Orban T, Ascherio A. Preclinical serum 25-hydroxyvitamin D levels and risk of type 1 diabetes in a cohort of US military personnel. Am J Epidemiol. 2013;177(5):411-419. doi:10.1093/aje/kws243 23380046
313 Bizzarri C, Pitocco D, Napoli N, et al. No protective effect of calcitriol on β-cell function in recent-onset type 1 diabetes: the IMDIAB XIII trial. Diabetes Care. 2010;33(9):1962-1963. doi:10.2337/dc10-0814 20805274
314 Walter M, Kaupper T, Adler K, Foersch J, Bonifacio E, Ziegler AG. No effect of the 1α,25-dihydroxyvitamin D3 on β-cell residual function and insulin requirement in adults with new-onset type 1 diabetes. Diabetes Care. 2010;33(7):1443-1448. doi:10.2337/dc09-2297 20357369
315 Manousaki D, Mitchell R, Dudding T, et al. Genome-wide association study for vitamin D levels reveals 69 independent loci. Am J Hum Genet. 2020;106(3):327-337. doi:10.1016/j.ajhg.2020.01.017 32059762
316 Cooper JD, Smyth DJ, Walker NM, et al. Inherited variation in vitamin D genes is associated with predisposition to autoimmune disease type 1 diabetes. Diabetes. 2011;60(5):1624-1631. doi:10.2337/db10-1656 21441443
317 Frederiksen BN, Kroehl M, Fingerlin TE, et al. Association between vitamin D metabolism gene polymorphisms and risk of islet autoimmunity and progression to type 1 diabetes: the Diabetes Autoimmunity Study in the Young (DAISY). J Clin Endocrinol Metab. 2013;98(11):E1845-E1851. doi:10.1210/jc.2013-2256 23979957
318 Mokry LE, Ross S, Ahmad OS, et al. Vitamin D and risk of multiple sclerosis: a Mendelian randomization study. PLoS Med. 2015;12(8):e1001866. doi:10.1371/journal.pmed.1001866 26305103
319 Manousaki D, Harroud A, Mitchell RE, et al. Vitamin D levels and risk of type 1 diabetes: a Mendelian randomization study. PLoS Med. 2021;18(2):e1003536. doi:10.1371/journal.pmed.1003536 33630834
320 Beales PE, Williams AJ, Albertini MC, Pozzilli P. Vitamin E delays diabetes onset in the non-obese diabetic mouse. Horm Metab Res. 1994;26(10):450-452. doi:10.1055/s-2007-1001731 7851866
321 Murthy VK, Shipp JC, Hanson C, Shipp DM. Delayed onset and decreased incidence of diabetes in BB rats fed free radical scavengers. Diabetes Res Clin Pract. 1992;18(1):11-16. doi:10.1016/0168-8227(92)90049-w 1446573
322 Knekt P, Reunanen A, Marniemi J, Leino A, Aromaa A. Low vitamin E status is a potential risk factor for insulin-dependent diabetes mellitus. J Intern Med. 1999;245(1):99-102. doi:10.1046/j.1365-2796.1999.00416.x 10095823
323 Uusitalo L, Nevalainen J, Niinistö S, et al. Serum a- and g-tocopherol concentrations and risk of advanced beta cell autoimmunity in children with HLA-conferred susceptibility to type 1 diabetes mellitus. Diabetologia. 2008;51(5):773-780. doi:10.1007/s00125-008-0959-2 18317723
324 Mattila M, Erlund I, Lee HS, et al. Plasma ascorbic acid and the risk of islet autoimmunity and type 1 diabetes: the TEDDY study. Diabetologia. 2020;63(2):278-286. doi:10.1007/s00125-019-05028-z 31728565
325 Djuricic I, Calder PC. Beneficial outcomes of omega-6 and omega-3 polyunsaturated fatty acids on human health: an update for 2021. Nutrients. 2021;13(7):2421. doi:10.3390/nu13072421 34371930
326 Norris JM, Yin X, Lamb MM, et al. Omega-3 polyunsaturated fatty acid intake and islet autoimmunity in children at increased risk for type 1 diabetes. JAMA. 2007;298(12):1420-1428. doi:10.1001/jama.298.12.1420 17895458
327 Norris JM, Kroehl M, Fingerlin TE, et al. Erythrocyte membrane docosapentaenoic acid levels are associated with islet autoimmunity: the Diabetes Autoimmunity Study in the Young. Diabetologia. 2014;57(2):295-304. doi:10.1007/s00125-013-3106-7 24240437
328 Niinistö S, Erlund I, Lee HS, et al. Children’s erythrocyte fatty acids are associated with the risk of islet autoimmunity. Sci Rep. 2021;11(1):3627. doi:10.1038/s41598-021-82200-9 33574451
329 Hakola L, Erlund I, Cuthbertson D, et al. Serum fatty acids and risk of developing islet autoimmunity: a nested case-control study within the TRIGR birth cohort. Pediatr Diabetes. 2021;22(4):577-585. doi:10.1111/pedi.13189 33543815
330 Wenzlau JM, Juhl K, Yu L, et al. The cation efflux transporter ZnT8 (Slc30A8) is a major autoantigen in human type 1 diabetes. Proc Natl Acad Sci U S A. 2007;104(43):17040-17045. doi:10.1073/pnas.0705894104 17942684
331 Wenzlau JM, Liu Y, Yu L, et al. A common nonsynonymous single nucleotide polymorphism in the SLC30A8 gene determines ZnT8 autoantibody specificity in type 1 diabetes. Diabetes. 2008;57(10):2693-2697. doi:10.2337/db08-0522 18591387
332 Sladek R, Rocheleau G, Rung J, et al. A genome-wide association study identifies novel risk loci for type 2 diabetes. Nature. 2007;445(7130):881-885. doi:10.1038/nature05616 17293876
333 Howson JM, Krause S, Stevens H, et al. Genetic association of zinc transporter 8 (ZnT8) autoantibodies in type 1 diabetes cases. Diabetologia. 2012;55(7):1978-1984. doi:10.1007/s00125-012-2540-2 22526605
334 Hägglöf B, Marklund SL, Holmgren G. CuZn superoxide dismutase, Mn superoxide dismutase, catalase and glutathione peroxidase in lymphocytes and erythrocytes in insulin-dependent diabetic children. Acta Endocrinologica. 1983;102(2):235-239. doi:10.1530/acta.0.1020235 6338671
335 Walter RM, Jr., Uriu-Hare JY, Olin KL, et al. Copper, zinc, manganese, and magnesium status and complications of diabetes mellitus. Diabetes Care. 1991;14(11):1050-1056. doi:10.2337/diacare.14.11.1050 1797486
336 Stene LC, Hongve D, Magnus P, Rønningen KS, Joner G. Acidic drinking water and risk of childhood-onset type 1 diabetes. Diabetes Care. 2002;25(9):1534-1538. doi:10.2337/diacare.25.9.1534 12196423
337 Samuelsson U, Oikarinen S, Hyöty H, Ludvigsson J. Low zinc in drinking water is associated with the risk of type 1 diabetes in children. Pediatr Diabetes. 2011;12(3 Pt 1):156-164. doi:10.1111/j.1399-5448.2010.00678.x 20920146
338 Kyvsgaard JN, Overgaard AJ, Jacobsen LD, et al. Low perinatal zinc status is not associated with the risk of type 1 diabetes in children. Pediatr Diabetes. 2017;18(7):637-642. doi:10.1111/pedi.12476 27873432
339 Lamb MM, Yin X, Barriga K, et al. Dietary glycemic index, development of islet autoimmunity, and subsequent progression to type 1 diabetes in young children. J Clin Endocrinol Metab. 2008;93(10):3936-3942. doi:10.1210/jc.2008-0886 18682514
340 Lamb MM, Frederiksen B, Seifert JA, Kroehl M, Rewers M, Norris JM. Sugar intake is associated with progression from islet autoimmunity to type 1 diabetes: the Diabetes Autoimmunity Study in the Young. Diabetologia. 2015;58(9):2027-2034. doi:10.1007/s00125-015-3657-x 26048237
341 Eizirik DL, Szymczak F, Alvelos MI, Martin F. From pancreatic β-cell gene networks to novel therapies for type 1 diabetes. Diabetes. 2021;70(9):1915-1925. doi:10.2337/dbi20-0046 34417266
342 Stene LC, Magnus P, Lie RT, Søvik O, Joner G, Norwegian Childhood Diabetes Study Group. Birth weight and childhood onset type 1 diabetes: population based cohort study. BMJ. 2001;322(7291):889-892. doi:10.1136/bmj.322.7291.889 11302899
343 Waernbaum I, Dahlquist G, Lind T. Perinatal risk factors for type 1 diabetes revisited: a population-based register study. Diabetologia. 2019;62(7):1173-1184. doi:10.1007/s00125-019-4874-5 31041471
344 Cardwell CR, Stene LC, Joner G, et al. Birthweight and the risk of childhood-onset type 1 diabetes: a meta-analysis of observational studies using individual patient data. Diabetologia. 2010;53(4):641-651. doi:10.1007/s00125-009-1648-5 20063147
345 Harder T, Roepke K, Diller N, Stechling Y, Dudenhausen JW, Plagemann A. Birth weight, early weight gain, and subsequent risk of type 1 diabetes: systematic review and meta-analysis. Am J Epidemiol. 2009;169(12):1428-1436. doi:10.1093/aje/kwp065 19363100
346 Hyppönen E, Kenward MG, Virtanen SM, et al. Infant feeding, early weight gain, and risk of type 1 diabetes. Childhood Diabetes in Finland (DiMe) Study Group. Diabetes Care. 1999;22(12):1961-1965. doi:10.2337/diacare.22.12.1961 10587826
347 EURODIAB Substudy 2 Study Group. Rapid early growth is associated with increased risk of childhood type 1 diabetes in various European populations. Diabetes Care. 2002;25(10):1755-1760. doi:10.2337/diacare.25.10.1755 12351473
348 Beyerlein A, Thiering E, Pflueger M, et al. Early infant growth is associated with the risk of islet autoimmunity in genetically susceptible children. Pediatr Diabetes. 2014;15(7):534-542. doi:10.1111/pedi.12118 24785566
349 Couper JJ, Beresford S, Hirte C, et al. Weight gain in early life predicts risk of islet autoimmunity in children with a first-degree relative with type 1 diabetes. Diabetes Care. 2009;32(1):94-99. doi:10.2337/dc08-0821 18835948
350 Magnus MC, Olsen SF, Granström C, et al. Infant growth and risk of childhood-onset type 1 diabetes in children from 2 Scandinavian birth cohorts. JAMA Pediatr. 2015;169(12):e153759. doi:10.1001/jamapediatrics.2015.3759 26642117
351 Elding Larsson H, Vehik K, Haller MJ, et al. Growth and risk for islet autoimmunity and progression to type 1 diabetes in early childhood: The Environmental Determinants of Diabetes in the Young Study. Diabetes. 2016;65(7):1988-1995. doi:10.2337/db15-1180 26993064
352 Elding Larsson H, Hansson G, Carlsson A, et al. Children developing type 1 diabetes before 6 years of age have increased linear growth independent of HLA genotypes. Diabetologia. 2008;51(9):1623-1630. doi:10.1007/s00125-008-1074-0 18592208
353 Lamb MM, Yin X, Zerbe GO, et al. Height growth velocity, islet autoimmunity and type 1 diabetes development: the Diabetes Autoimmunity Study in the Young. Diabetologia. 2009;52(10):2064-2071. doi:10.1007/s00125-009-1428-2 19547949
354 Liu X, Vehik K, Huang Y, et al. Distinct growth phases in early life associated with the risk of type 1 diabetes: the TEDDY study. Diabetes Care. 2020;43(3):556-562. doi:10.2337/dc19-1670 31896601
355 Jeffery AN, Metcalf BS, Hosking J, Streeter AJ, Voss LD, Wilkin TJ. Age before stage: insulin resistance rises before the onset of puberty: a 9-year longitudinal study (EarlyBird 26). Diabetes Care. 2012;35(3):536-541. doi:10.2337/dc11-1281 22279034
356 Gale EA, Gillespie KM. Diabetes and gender. Diabetologia. 2001;44(1):3-15. doi:10.1007/s001250051573 11206408
357 Skog O, Korsgren O. Aetiology of type 1 diabetes: physiological growth in children affects disease progression. Diabetes Obes Metab. 2018;20(4):775-785. doi:10.1111/dom.13144 29083510
358 Meah FA, DiMeglio LA, Greenbaum CJ, et al. The relationship between BMI and insulin resistance and progression from single to multiple autoantibody positivity and type 1 diabetes among TrialNet Pathway to Prevention participants. Diabetologia. 2016;59(6):1186-1195. doi:10.1007/s00125-016-3924-5 26995649
359 Winkler C, Marienfeld S, Zwilling M, Bonifacio E, Ziegler AG. Is islet autoimmunity related to insulin sensitivity or body weight in children of parents with type 1 diabetes? Diabetologia. 2009;52(10):2072-2078. doi:10.1007/s00125-009-1461-1 19641897
360 Wilkin TJ. The accelerator hypothesis: weight gain as the missing link between type I and type II diabetes. Diabetologia. 2001;44(7):914-922. doi:10.1007/s001250100548 11508279
361 Viner RM, Hindmarsh PC, Taylor B, Cole TJ. Childhood body mass index (BMI), breastfeeding and risk of type 1 diabetes: findings from a longitudinal national birth cohort. Diabet Med. 2008;25(9):1056-1061. doi:10.1111/j.1464-5491.2008.02525.x 19183310
362 Nucci AM, Virtanen SM, Cuthbertson D, et al. Growth and development of islet autoimmunity and type 1 diabetes in children genetically at risk. Diabetologia. 2021;64(4):826-835. doi:10.1007/s00125-020-05358-3 33474583
363 Antvorskov JC, Aunsholt L, Buschard K, et al. Childhood body mass index in relation to subsequent risk of type 1 diabetes—a Danish cohort study. Pediatr Diabetes. 2018;19(2):265-270. doi:10.1111/pedi.12568 28940941
364 Zucker I, Zloof Y, Bardugo A, et al. Obesity in late adolescence and incident type 1 diabetes in young adulthood. Diabetologia. 2022;65(9):1473-1482. doi:10.1007/s00125-022-05722-5 35665825
365 Elias D, Prigozin H, Polak N, Rapoport M, Lohse AW, Cohen IR. Autoimmune diabetes induced by the beta-cell toxin STZ. Immunity to the 60-kDa heat shock protein and to insulin. Diabetes. 1994;43(8):992-998. doi:10.2337/diab.43.8.992 8039607
366 Kantwerk-Funke G, Burkart V, Kolb H. Low dose streptozotocin causes stimulation of the immune system and of anti-islet cytotoxicity in mice. Clin Exp Immunol. 1991;86(2):266-270. doi:10.1111/j.1365-2249.1991.tb05808.x 1657463
367 Myers MA, Mackay IR, Zimmet PZ. Toxic type 1 diabetes. Rev Endocr Metab Disord. 2003;4(3):225-231. doi:10.1023/a:1025196127517 14501173
368 Karam JH, Lewitt PA, Young CW, et al. Insulinopenic diabetes after rodenticide (Vacor) ingestion: a unique model of acquired diabetes in man. Diabetes. 1980;29(12):971-978. doi:10.2337/diab.29.12.971 6777223
369 Bodin J, Stene LC, Nygaard UC. Can exposure to environmental chemicals increase the risk of diabetes type 1 development? Biomed Res Int. 2015;2015:208947. doi:10.1155/2015/208947 25883945
370 Rignell-Hydbom A, Elfving M, Ivarsson SA, et al. A nested case-control study of intrauterine exposure to persistent organochlorine pollutants in relation to risk of type 1 diabetes. PLoS One. 2010;5(6):e11281. doi:10.1371/journal.pone.0011281 20585661
371 Salo HM, Koponen J, Kiviranta H, et al. No evidence of the role of early chemical exposure in the development of beta-cell autoimmunity. Environ Sci Pollut Res Int. 2019;26(2):1370-1378. doi:10.1007/s11356-018-3659-6 30426368
372 Bresson SE, Isom S, Jensen ET, et al. Associations between persistent organic pollutants and type 1 diabetes in youth. Environ Int. 2022;163:107175. doi:10.1155/2015/208947 35303528
373 Howard SG. Exposure to environmental chemicals and type 1 diabetes: an update. J Epidemiol Community Health. 2019;73(6):483-488. doi:10.1136/jech-2018-210627 30862699
374 Malmqvist E, Elding Larsson H, Jönsson I, et al. Maternal exposure to air pollution and type 1 diabetes—accounting for genetic factors. Environ Res. 2015;140:268-74. doi:10.1016/j.envres.2015.03.024 25880886
375 Sheehan A, Freni Sterrantino A, Fecht D, Elliott P, Hodgson S. Childhood type 1 diabetes: an environment-wide association study across England. Diabetologia. 2020;63(5):964-976. doi:10.1007/s00125-020-05087-7 31980846
376 Morgenstern H, Wakefield J. Ecologic Studies and Analysis. In: Lash TL, VanderWeele TJ, Haneuse S, Rothman KJ, eds. Modern Epidemiology. 4th ed. Wolters Kluwer; 2021:chap 30.
377 Faresjö M. The link between psychological stress and autoimmune response in children. Crit Rev Immunol. 2015;35(2):117-134. doi:10.1615/critrevimmunol.2015013255 26351146
378 Sepa A, Wahlberg J, Vaarala O, Frodi A, Ludvigsson J. Psychological stress may induce diabetes-related autoimmunity in infancy. Diabetes Care. 2005;28(2):290-295. doi:10.2337/diacare.28.2.290 15677781
379 Sepa A, Frodi A, Ludvigsson J. Mothers’ experiences of serious life events increase the risk of diabetes-related autoimmunity in their children. Diabetes Care. 2005;28(10):2394-2399. doi:10.2337/diacare.28.10.2394 16186269
380 Barker JM, Barriga KJ, Yu L, et al. Prediction of autoantibody positivity and progression to type 1 diabetes: Diabetes Autoimmunity Study in the Young (DAISY). J Clin Endocrinol Metab. 2004;89(8):3896-3902. doi:10.1210/jc.2003-031887 15292324
381 Nygren M, Carstensen J, Koch F, Ludvigsson J, Frostell A. Experience of a serious life event increases the risk for childhood type 1 diabetes: the ABIS population-based prospective cohort study. Diabetologia. 2015;58(6):1188-1197. doi:10.1007/s00125-015-3555-2 25870022
382 Lundgren M, Ellström K, Elding Larsson H, DiPiS Study Group. Influence of early-life parental severe life events on the risk of type 1 diabetes in children: the DiPiS study. Acta Diabetol. 2018;55(8):797-804. doi:10.1007/s00592-018-1150-y 29752553
383 Johnson SB, Lynch KF, Roth R, et al. First-appearing islet autoantibodies for type 1 diabetes in young children: maternal life events during pregnancy and the child’s genetic risk. Diabetologia. 2021;64(3):591-602. doi:10.1007/s00125-020-05344-9 33404683
384 Virk J, Li J, Vestergaard M, Obel C, Lu M, Olsen J. Early life disease programming during the preconception and prenatal period: making the link between stressful life events and type-1 diabetes. PLoS One. 2010;5(7):e11523. doi:10.1371/journal.pone.0011523 20634978
385 Virk J, Ritz B, Li J, Obel C, Olsen J. Childhood bereavement and type 1 diabetes: a Danish national register study. Paediatr Perinat Epidemiol. 2016;30(1):86-92. doi:10.1111/ppe.12247 26444317
386 Bengtsson J, Byberg S, Carstensen B, et al. Accumulation of childhood adversities and type 1 diabetes risk: a register-based cohort study of all children born in Denmark between 1980 and 2015. Int J Epidemiol. 2020;49(5):1604-1613. doi:10.1093/ije/dyaa138 33005951
387 Bengtsson J, Rieckmann A, Carstensen B, Svensson J, Jørgensen ME, Rod NH. Trajectories of childhood adversity and type 1 diabetes: a nationwide study of one million children. Diabetes Care. 2021;44(3):740-747. doi:10.2337/dc20-1130 33495291
388 Gomez-Lopera N, Pineda-Trujillo N, Diaz-Valencia PA. Correlating the global increase in type 1 diabetes incidence across age groups with national economic prosperity: a systematic review. World J Diabetes. 2019;10(12):560-580. doi:10.4239/wjd.v10.i12.560 31915518
389 Patterson CC, Dahlquist G, Soltész G, Green A, EURODIAB ACE Study Group. Is childhood-onset type I diabetes a wealth-related disease? An ecological analysis of European incidence rates. Diabetologia. 2001;44(Suppl 3):B9-B16. doi:10.1007/pl00002961 11724424
390 Lopez-Doriga Ruiz P, Stene LC. Is socio-economic status associated with risk of childhood type 1 diabetes? Literature review. Diabet Med. 2023;40(10):e15182. doi:10.1111/dme.15182 37489698
391 D’Angeli MA, Merzon E, Valbuena LF, Tirschwell D, Paris CA, Mueller BA. Environmental factors associated with childhood-onset type 1 diabetes mellitus: an exploration of the hygiene and overload hypotheses. Arch Pediatr Adolesc Med. 2010;164(8):732-738. doi:10.1001/archpediatrics.2010.115 20679164
392 Cardwell CR, Stene LC, Joner G, et al. Maternal age at birth and childhood type 1 diabetes: a pooled analysis of 30 observational studies. Diabetes. 2010;59(2):486-494. doi:10.2337/db09-1166 19875616
393 Blom L, Dahlquist G, Nyström L, Sandström A, Wall S. The Swedish childhood diabetes study—social and perinatal determinants for diabetes in childhood. Diabetologia. 1989;32(1):7-13. doi:10.1007/BF00265397 2707518
394 Stene LC, Magnus P, Lie RT, Søvik O, Joner G, Norwegian Childhood Diabetes Study Group. Maternal and paternal age at delivery, birth order, and risk of childhood onset type 1 diabetes: population based cohort study. BMJ. 2001;323(7309):369-371. doi:10.1136/bmj.323.7309.369 11509426
395 Magnus MC, Olsen SF, Granström C, et al. Paternal and maternal obesity but not gestational weight gain is associated with type 1 diabetes. Int J Epidemiol. 2018;47(2):417-426. doi:10.1093/ije/dyx266 29415279
396 Hidayat K, Zou SY, Shi BM. The influence of maternal body mass index, maternal diabetes mellitus, and maternal smoking during pregnancy on the risk of childhood-onset type 1 diabetes mellitus in the offspring: systematic review and meta-analysis of observational studies. Obes Rev. 2019;20(8):1106-1120. doi:10.1111/obr.12858 31090253
397 Arkkola T, Kautiainen S, Takkinen HM, et al. Relationship of maternal weight status and weight gain rate during pregnancy to the development of advanced beta cell autoimmunity in the offspring: a prospective birth cohort study. Pediatr Diabetes. 2011;12(5):478-484. doi:10.1111/j.1399-5448.2010.00703.x 21129139
398 Thavagnanam S, Fleming J, Bromley A, Shields MD, Cardwell CR. A meta-analysis of the association between Caesarean section and childhood asthma. Clin Exp Allergy. 2008;38(4):629-633. doi:10.1111/j.1365-2222.2007.02780.x 18352976
399 Clausen TD, Bergholt T, Eriksson F, Rasmussen S, Keiding N, Løkkegaard EC. Prelabor cesarean section and risk of childhood type 1 diabetes: a nationwide register-based cohort study. Epidemiology. 2016;27(4):547-555. doi:10.1097/ede.0000000000000488 27031040
400 Khashan AS, Kenny LC, Lundholm C, et al. Gestational age and birth weight and the risk of childhood type 1 diabetes: a population-based cohort and sibling design study. Diabetes Care. 2015;38(12):2308-2315. doi:10.2337/dc15-0897 26519334
401 Dahlquist G, Källén B. Maternal-child blood group incompatibility and other perinatal events increase the risk for early-onset type 1 (insulin- dependent) diabetes mellitus. Diabetologia. 1992;35(7):671-675. doi:10.1007/bf00400261 1644246
402 Magnus MC, Tapia G, Olsen SF, et al. Parental smoking and risk of childhood-onset type 1 diabetes. Epidemiology. 2018;29(6):848-856. doi:10.1097/ede.0000000000000911 30074542
403 Wei Y, Andersson T, Edstorp J, et al. Maternal smoking during pregnancy and type 1 diabetes in the offspring: a nationwide register-based study with family-based designs. BMC Med. 2022;20(1):240. doi:10.1186/s12916-022-02447-5 35953788
404 Edstorp J, Lampousi AM, Carlsson S. Parental smoking, type 1 diabetes, and islet autoantibody positivity in the offspring: a systematic review and meta-analysis. Diabet Med. 2022;39(6):e14830. doi:10.1111/dme.14830 35290684
405 Metsälä J, Hakola L, Lundqvist A, Virta LJ, Gissler M, Virtanen SM. Perinatal factors and the risk of type 1 diabetes in childhood and adolescence. A register-based case-cohort study in Finland, years 1987 to 2009. Pediatr Diabetes. 2020;21(4):586-596. doi:10.1111/pedi.12994 32003515
406 Li S, Zhang M, Tian H, Liu Z, Yin X, Xi B. Preterm birth and risk of type 1 and type 2 diabetes: systematic review and meta-analysis. Obes Rev. 2014;15(10):804-811. doi:10.1111/obr.12214 25073871
407 Warram JH, Krolewski AS, Gottlieb MS, Kahn CR. Differences in risk of insulin-dependent diabetes in offspring of diabetic mothers and diabetic fathers. N Engl J Med. 1984;311(3):149-152. doi:10.1056/NEJM198407193110304 6738600
408 Harjutsalo V, Reunanen A, Tuomilehto J. Differential transmission of type 1 diabetes from diabetic fathers and mothers to their offspring. Diabetes. 2006;55(5):1517-1524. doi:10.2337/db05-1296 16644714
409 Hastie T, Tibshirani R, Friedman J. The Elements of Statistical Learning. 2nd ed. Springer; 2009.
410 van der Ploeg T, Austin PC, Steyerberg EW. Modern modelling techniques are data hungry: a simulation study for predicting dichotomous endpoints. BMC Med Res Methodol. 2014;14:137. doi:10.1186/1471-2288-14-137 25532820
411 Orešič M, Simell S, Sysi-Aho M, et al. Dysregulation of lipid and amino acid metabolism precedes islet autoimmunity in children who later progress to type 1 diabetes. J Exp Med. 2008;205(13):2975-2984. doi:10.1084/jem.20081800 19075291
412 Pflueger M, Seppänen-Laakso T, Suortti T, et al. Age- and islet autoimmunity-associated differences in amino acid and lipid metabolites in children at risk for type 1 diabetes. Diabetes. 2011;60(11):2740-2747. doi:10.2337/db10-1652 22025777
413 La Torre D, Seppänen-Laakso T, Larsson HE, et al. Decreased cord-blood phospholipids in young age-at-onset type 1 diabetes. Diabetes. 2013;62(11):3951-3956. doi:10.2337/db13-0215 23929934
414 Orešič M, Gopalacharyulu P, Mykkänen J, et al. Cord serum lipidome in prediction of islet autoimmunity and type 1 diabetes. Diabetes. 2013;62(9):3268-3274. doi:10.2337/db13-0159 23630305
415 Lamichhane S, Kemppainen E, Trošt K, et al. Circulating metabolites in progression to islet autoimmunity and type 1 diabetes. Diabetologia. 2019;62(12):2287-2297. doi:10.1007/s00125-019-04980-0 31444528
416 Li Q, Parikh H, Butterworth MD, et al. Longitudinal metabolome-wide signals prior to the appearance of a first islet autoantibody in children participating in the TEDDY study. Diabetes. 2020;69(3):465-476. doi:10.2337/db19-0756 32029481
417 Li Q, Liu X, Yang J, et al. Plasma metabolome and circulating vitamins stratified onset age of an initial islet autoantibody and progression to type 1 diabetes: the TEDDY study. Diabetes. 2021;70(1):282-292. doi:10.2337/db20-0696 33106256
418 Webb-Robertson BM, Bramer LM, Stanfill BA, et al. Prediction of the development of islet autoantibodies through integration of environmental, genetic, and metabolic markers. J Diabetes. 2021;13(2):143-153. doi:10.1111/1753-0407.13093 33124145
419 Webb-Robertson BM, Nakayasu ES, Frohnert BI, et al. Integration of infant metabolite, genetic and islet autoimmunity signatures to predict type 1 diabetes by 6 years of age. J Clin Endocrinol Metab. 2022;107(8):2329-2338. doi:10.1210/clinem/dgac225 35468213
420 Frohnert BI, Webb-Robertson BJ, Bramer LM, et al. Predictive modeling of type 1 diabetes stages using disparate data sources. Diabetes. 2020;69(2):238-248. doi:10.2337/db18-1263 31740441
421 Tsai YW, Dong JL, Jian YJ, et al. Gut microbiota-modulated metabolomic profiling shapes the etiology and pathogenesis of autoimmune diseases Microorganisms. 2021;9(9). doi:10.3390/microorganisms9091930
422 Johnson RK, Vanderlinden L, DeFelice BC, et al. Metabolite-related dietary patterns and the development of islet autoimmunity. Sci Rep. 2019;9(1):14819. doi:10.1038/s41598-019-51251-4 31616039
423 Johnson RK, Vanderlinden LA, DeFelice BC, et al. Metabolomics-related nutrient patterns at seroconversion and risk of progression to type 1 diabetes. Pediatr Diabetes. 2020;21(7):1202-1209. doi:10.1111/pedi.13085 32686271
424 Stene LC, Rønningen KS, Magnus P, Joner G. Does HLA genotype influence the relative risk of type 1 diabetes conferred by dietary factors? Diabet Med. 2002;19(5):429-431. doi:10.1046/j.1464-5491.2002.00672_2.x
425 Perez-Bravo F, Carrasco E, Gutierrez-López MD, Martinez MT, López G, de los Rios MG. Genetic predisposition and environmental factors leading to the development of insulin-dependent diabetes mellitus in Chilean children. J Mol Med (Berl). 1996;74(2):105-109. doi:10.1007/bf00196786 8820406
426 Kostraba JN, Cruickshanks KJ, Lawler-Heavner J, et al. Early exposure to cow’s milk and solid foods in infancy, genetic predisposition, and risk of IDDM. Diabetes. 1993;42(2):288-295. doi:10.2337/diab.42.2.288 8425665
427 Lempainen J, Vaarala O, Mäkelä M, et al. Interplay between PTPN22 C1858T polymorphism and cow’s milk formula exposure in type 1 diabetes. J Autoimmun. 2009;33(2):155-164. doi:10.1016/j.jaut.2009.04.003 19473815
428 Stene LC, Thorsby PM, Berg JP, Rønningen KS, Joner G, Norwegian Childhood Diabetes Study Group. Peroxisome proliferator-activated receptor-g2 Pro12Ala polymorphism, cod liver oil and risk of type 1 diabetes. Pediatr Diabetes. 2008;9(1):40-45. doi:10.1111/j.1399-5448.2007.00263.x 18211635
429 Voruganti VS, Higgins PB, Ebbesson SO, et al. Variants in CPT1A, FADS1, and FADS2 are associated with higher levels of estimated plasma and erythrocyte delta-5 desaturases in Alaskan Eskimos. Front Genet. 2012;3:86. doi:10.3389/fgene.2012.00086 22701466
430 Tapia G, Mårild K, Dahl SR, et al. Maternal and newborn vitamin D-binding protein, vitamin D levels, vitamin D receptor genotype, and childhood type 1 diabetes. Diabetes Care. 2019;42(4):553-559. doi:10.2337/dc18-2176 30692241
431 Bonifacio E, Warncke K, Winkler C, Wallner M, Ziegler AG. Cesarean section and interferon-induced helicase gene polymorphisms combine to increase childhood type 1 diabetes risk. Diabetes. 2011;60(12):3300-3306. doi:10.2337/db11-0729 22110093
432 Stene LC, Rønningen KS, Undlien DE, Joner G. Does the relative risk for type 1 diabetes conferred by HLA-DQ, INS, and PTPN22 polymorphisms vary with maternal age, birth weight, or cesarean section? Pediatr Diabetes. 2011;12(2):91-94. doi:10.1111/j.1399-5448.2010.00669.x 21352425
433 Wild CP. The exposome: from concept to utility. Int J Epidemiol. 2012;41(1):24-32. doi:10.1093/ije/dyr236 22296988
434 Vermeulen R, Schymanski EL, Barabási AL, Miller GW. The exposome and health: where chemistry meets biology. Science. 2020;367(6476):392-396. doi:10.1126/science.aay3164 31974245
435 Miller GW. Integrating the exposome into a multi-omic research framework. Exposome. 2021;1(1):osab002. doi:10.1093/exposome/osab002 37538530
436 Laiho JE, Laitinen OH, Malkamäki J, et al. Exposomic determinants of immune-mediated diseases: special focus on type 1 diabetes, celiac disease, asthma, and allergies: the HEDIMED project approach. Environ Epidemiol. 2022;6(3):e212. doi:10.1097/ee9.0000000000000212 35702504
437 Lönnrot M, Korpela K, Knip M, et al. Enterovirus infection as a risk factor for β-cell autoimmunity in a prospectively observed birth cohort: the Finnish Diabetes Prediction and Prevention Study. Diabetes. 2000;49(8):1314-1318. doi:10.2337/diabetes.49.8.1314 10923631
438 Fronczak CM, Barón AE, Chase HP, et al. In utero dietary exposures and risk of islet autoimmunity in children. Diabetes Care. 2003;26(12):3237-3242. doi:10.2337/diacare.26.12.3237 14633808
439 Virtanen SM, Niinistö S, Nevalainen J, et al. Serum fatty acids and risk of advanced beta-cell autoimmunity: a nested case-control study among children with HLA-conferred susceptibility to type I diabetes. Eur J Clin Nutr. 2010;64(8):792-799. doi:10.1038/ejcn.2010.75 20502469
440 Syrjälä E, Nevalainen J, Peltonen J, et al. A joint modeling approach for childhood meat, fish and egg consumption and the risk of advanced islet autoimmunity. Sci Rep. 2019;9(1):7760. doi:10.1038/s41598-019-44196-1 31123290

FIGURE 1.

Time Trends in Incidence of Type 1 Diabetes Per 100,000 Per Year in Children, 1960–2021.

Incidence rates are shown for age-group 0–14 years, except Germany 2011–2021 (age 0.5–17 years) and Mexico (age 0–19 years). Data are nationwide, except Germany up to 2006, United States, and Algeria. Note overlapping sources for Finland: the lower curve is from the Finnish Pediatric Diabetes Register, which had 90% ascertainment but more recent data (2012–2018). Incidence data from the United States (SEARCH) are for age-group 0–14 years, which was approximately 10%–15% higher than that for the 0–19 years group. SEARCH, SEARCH for Diabetes in Youth study.

SOURCE: Original figure constructed by L. C. Stene, using data from references 10, 11, 12, 13, 14, 15, 16, 17, 18, 19, 20, 21, 22, 23, 24, 25, and 26

FIGURE 2.

Stages of Type 1 Diabetes.

Panel A: GAD, glutamic acid decarboxylase; IA-2, insulinoma antigen 2; ZnT8, zinc transporter 8. Panel B: For assessment of factors modifying the incidence of islet autoantibody seroconversion, exposures in the period before seroconversion in islet autoimmunity cases (child 1 and child 2) are compared with the corresponding period in children who do not seroconvert during the same follow-up time (child 3), e.g., vertical arrow 1. For assessment of factors modifying the rate of progression from islet autoimmunity to clinical type 1 diabetes, exposure must be studied in the period after seroconversion, but before type 1 diabetes onset. Exposure in children developing type 1 diabetes is compared with the same period for children who do not develop type 1 diabetes during the same follow-up period, e.g., vertical arrow 2. This principle applies to cohort studies and nested case-control studies. Any difference in exposure between child 2 and child 3 in the period after seroconversion, e.g., vertical arrow 3, could be influenced by reverse causation if involving biomarkers or other measures of exposure that could conceivably be influenced by autoimmunity.

* No islet autoimmunity (open circles)

† Islet autoimmunity (closed circles)

‡ Clinical type 1 diabetes

SOURCE: Panel A: Original figure constructed by M. Rewers. Panel B: Adapted from reference 34.

FIGURE 3.

Risk Factors by Stage of Type 1 Diabetes in the TEDDY Study.

See also Figure 4 for more details on the virus association. FDR, first-degree relatives of someone with type 1 diabetes (some differences in hazard ratios were observed depending on type of FDR and first-appearing autoantibody); GAD, glutamic acid decarboxylase; HLA, human leukocyte antigen (here, comparing among selected high- to moderate-risk genotypes included in TEDDY); HR, hazard ratio; IA-2, insulinoma antigen 2; SD, standard deviation; SNP, single nucleotide polymorphism; TEDDY, The Environmental Determinants of Diabetes in the Young study; ZnT8, zinc transporter 8.

* Factors that were nominally significant (without correction for multiple testing) predictors in multivariable Cox regression. See reference 37 for rs-number/exact SNP and reference alleles. Hazard ratios per allele ranged from approximately 0.7 to 1.4, with most between 0.85 and 1.15. Most of these SNPs showed similar magnitude of association for islet autoimmunity overall (at least one islet autoantibody), insulin autoantibody first, and GAD autoantibodies first, although associations were not always significant for both subgroups. The clear exception was rs689 near the insulin gene (INS), which was a risk factor for insulin autoantibodies first, but not for GAD autoantibodies first.

† Hazard ratio comparing Finland versus United States or Germany was approximately 1.5. Not all pairwise country differences were statistically significant.

SOURCE: All data from reference 37, except Enterovirus B data from reference 131

FIGURE 4.

Longitudinal Fecal Virome and Association With Islet Autoimmunity in the TEDDY Study.

Associations are shown for common viruses in fecal samples. Panel A: increasing numbers of virus-positive samples (n=4,327 matched-pair samples; ln, log-linear association). Panel B: whether or not children were virus-positive from ages 3 to 6 months (n=370 matched-pair children). Panel C: whether or not children were positive for the virus in at least two consecutive samples (n=383 matched-pair children). Conditional logistic regression models were adjusted for the HLA-DR-DQ genotype. CI, confidence interval; EV, Enterovirus (species A–D); HAdV, human Adenovirus (species A–F); HLA, human leukocyte antigen; OR, odds ratio; TEDDY, The Environmental Determinants of Diabetes in the Young study.

* Statistically significant associations for enterovirus (a priori hypothesis) at P<0.05 or for other viruses that showed a false discovery rate (FDR) corrected q-value <0.05

SOURCE: Reference 131

FIGURE 5.

Risk of Developing Islet Autoimmunity Associated With Early Childhood 25(OH)D Concentrations by VDR Genotype in the TEDDY Study.

The number of minor alleles (the C allele) at rs7975232 is shown on the x-axis. Analyses were adjusted for HLA-DR3/4 and the first two principle components (PCs) indicating ancestry. Early infancy vitamin D measures included 360 case subjects with islet autoimmunity (≥1 confirmed, repeated islet autoantibody) and their control subjects; early infancy 25(OH)D samples included the first visit (mostly age 3–9 months) and all other available samples before age 12 months. The raw p-value for 25(OH)D x VDR SNP (rs7975232) interaction was 0.0019, and the false discovery rate corrected q-value was 0.017. 25(OH)D, 25-hydroxy vitamin D; CI, confidence interval; HLA, human leukocyte antigen; IA, islet autoimmunity; OR, odds ratio; SNP, single nucleotide polymorphism; TEDDY, The Environmental Determinants of Diabetes in the Young study; VDR, vitamin D receptor gene.

SOURCE: Reference 309

TABLE 1.

Cumulative Incidence, by Age 20 Years, of Type 1 Diabetes and Persistent Islet Autoimmunity in the General U.S. Population and Family Members of Type 1 Diabetes Patients

| TYPE 1 DIABETES | ISLET AUTOIMMUNITY
General population | 1:300 | 1:100
Family members
Maternal offspring | 1:40 | 1:15
Paternal offspring | 1:15 | 1:5
Siblings (all) | 1:12–1:35 | 1:7
HLA-identical sibling | 1:4 | 1:2
Monozygotic twins | 1:3 | 1:1

HLA, human leukocyte antigen.

SOURCE: References 41, 44, 45, 46, 47, 49, and 50

TABLE 2.

Proportion of Type 1 Diabetes Subjects With High-Risk HLA Genotypes

POPULATION (REF.) | PERCENTAGE (YEARS COVERED) | | | | | P-VALUE
POPULATION (REF.) | Before 1975 | 1975–1999 | | | 2000 or Later | P-VALUE
United States (BDC) (74) | 38% (1965–1974) | 37% (1975–1984) | 31% (1985–1994) | 26% (1995–2008) | | 0.02
United States (75) | | 41% (1978–1988) | | | 28% (2002–2004) | 0.05
T1DGC (74) | 49% (1965–1974) | 45% (1975–1984) | 39% (1985–1994) | 35% (1995–2008) | | <0.0001
Finland (76) | 25% (1939–1965) | | 18% (1990–2001) | | | 0.007
Australia (77) | 79% (1950–1969) | 60% (1970–1979) | 47% (1980–1989) | 37% (1990–1999) | 28% (2000–2005) | <0.0001
Sweden (78) | | | 36% (1986–1987) | 37% (1996–2000) | 19% (2003–2005) | <0.0001
Italy (79) | | | 23% (1980–1989) | 21% (1990–1999) | 27% (2000–2012) | NS
United Kingdom (80) | 47% (1922–1946)* | | 35% (1985–2002)

High-risk HLA genotypes are defined as: DR3-DQ2/DR4-DQ8 (80), (DR3)-DQA1*05-DQB1*02/ DRB1*0401-DQB1*0302 (76), DRB1*03-DQB1*0201/DRB1*04-DQB1*0302 (79), DR3-DQB1*0201/DR4-DQB1*0302 (74), DRB1*03-DQB1*02/DRB1*04-DQB1*03 (75), DR3/4 (77), HLA DQA1*-B1*genotype 0501-0201/0301-0302 (78). BDC, Barbara Davis Center for Diabetes; HLA, human leukocyte antigen; NS, nonsignificant; T1DGC, Type 1 Diabetes Genetics Consortium.

* Must have survived 50 years with type 1 diabetes to be tested.

SOURCE: References are listed within the table.

TABLE 3.

Longitudinal Studies of Enterovirus and Islet Autoimmunity or Type 1 Diabetes

STUDY, YEARS (REF.) | POPULATION* | AGE (MONTHS) AT SAMPLE COLLECTION | DEFINITION OF ISLET AUTOIMMUNITY; NUMBER OF CASES TESTED FOR ENTEROVIRUS | TYPE OF SAMPLE AND ENTEROVIRUS ASSAY
DiMe, 1986–1993 (126,147) | Siblings, Finland | 6-month intervals from type 1 diabetes diagnosis in sibling | ≥1 of ICA, IAA, GADA, IA-2A; 11 cases | Serum, serology, and RT-PCR
DIPP, 1994–ongoing (127,135,141,145,437) | Newborns with moderate- or high-risk HLA genes, Finland | Blood at birth, 3 months, and 6–12-month intervals up to 15 years; monthly stools from 3 to 48 months | ICA, IAA, GADA, IA-2A, later also ZnT8A; up to 20–183 cases in different publications | Binding and/or neutralizing antibodies, RT-PCR on serum and/or feces
Second pilot of TRIGR, 1995–1999 (152) | Newborns with family history of type 1 diabetes, Finland | Cord, 3, 6, 9, 12, 18, 24 | ≥1 of IAA, GADA, IA-2A, ICA; 19 cases | Serum, serology, and RT-PCR
DAISY, 1993–ongoing (87,144) | Relatives and newborns with HLA risk genes, Colorado | 9, 12, 15, 24, then annually; 3–6-month intervals from islet autoimmunity | ≥1 of IAA, GADA, IA-2A on ≥2 consecutive occasions; up to 26 cases or 140 cases for progression study | Serology, RT-PCR on both serum and rectal swabs
MIDIA, 2001–ongoing (134,146) | Newborns with high-risk HLA, Norway | Stool every month from 3 to 36 months; blood at 3, 6, 9, 12 months, then annually | ≥2 of IAA, GADA, IA-2A on ≥2 consecutive occasions; 27–48 cases | Fecal samples, RT-PCR on fecal samples and blood cell fraction
BABYDIAB, 1989–ongoing (143) | Offspring, Germany | Cord, 9, 24, 36, 60, 96 | ≥1 of IAA, GADA, IA-2A, ICA; 28 cases | Serum, coxsackievirus serology
BABYDIET, 2000–ongoing (133) | Relatives and newborns with HLA risk genes, Germany | 3, 6, 9, 12 | ≥1 of IAA, GADA, IA-2A, Zn-T8A; 22 cases | Fecal samples, RT-PCR, cell culture
VIGR, 2006–ongoing (137) | Relatives, Australia | Every 6 months from 6 to 30 months | ≥1 of IAA, GADA, IA-2A in ≥2 consecutive blood samples; 41 cases | Stool and plasma samples, virome-enriched sequencing (VirCapSeq), qRT-PCR for confirmation
TEDDY, 2004–2012 (and ongoing) (131) | Newborns with HLA risk genes, United States, Finland, Sweden, and Germany | Monthly stools to 48 months, then every 3 months to 10 years | ≥1 of IAA, GADA, IA-2A in ≥2 consecutive blood samples; 383 cases | Stool samples, sequencing, including culture enrichment

DAISY, Diabetes Autoimmunity Study in the Young; DiMe, Childhood Diabetes in Finland Study; DIPP, Diabetes Prediction and Prevention Study; EV, enterovirus; GADA, glutamic acid decarboxylase autoantibodies; HLA, human leukocyte antigen; IA, islet autoimmunity; IA-2A, insulinoma antigen 2 autoantibodies; IAA, insulin autoantibodies; ICA, islet cell autoantibodies; MIDIA, Environmental Triggers of Type 1 Diabetes study; qRT-PCR, quantitative RT-PCR; RT-PCR, reverse transcription-polymerase chain reaction; TEDDY, The Environmental Determinants of Diabetes in the Young study; TRIGR, Trial to Reduce IDDM in the Genetically at Risk; VIGR, Viruses In the Genetically at Risk; ZnT8A, zinc transporter 8 autoantibodies.

* Relatives (siblings, offspring, etc.) of people with type 1 diabetes

SOURCE: References are listed within the table.

TABLE 4.

Postnatal Enterovirus Infections Before Islet Autoimmunity and the Corresponding Period for Matched Controls From Longitudinal Birth Cohort Studies

TYPE OF ENTEROVIRUS ASSAY/SAMPLE AND STUDY (REF.) | PER SAMPLE RESULTS | PER SUBJECT RESULTS
TYPE OF ENTEROVIRUS ASSAY/SAMPLE AND STUDY (REF.) | EV+ Case Samples Versus EV+ Control Samples Odds Ratio (95% CI) | Case Subjects EV+ At Least Once Versus Controls Odds Ratio (95% CI)
EV RNA in feces
DIPP, any EV before islet autoimmunity (135) | NR | Mean 0.6 positive samples per 120 case children vs. mean 0.4 positive samples per 282 controls
MIDIA (134) | 43/339 (13%) vs. 94/692 (14%) OR 1.0 (0.6–1.7) | 18/27 (67%) vs. 30/53 (57%) OR 1.5 (0.6–4.0)
BABYDIET (133) | 5/72 (7%) vs. 27/267 (10%) OR 0.7 (0.2–2.2) | 4/22 (18%) vs. 20/82 (24%) OR 0.7 (0.2–2.3)
VIGR (at least one EV) (137)* | x/32 vs. x/32 OR 1.0* | NR
TEDDY (at least one Enterovirus A–D) ( 131 )† | OR ∼1.2 (1.0–1.3), per positive sample† | OR ∼1.0 (0.7–1.5)†
EV RNA in blood
DIPP (141) | NR | NR
TRIGR (152) | NR (14%) vs. NR (8.4%) OR 1.8 (NR) | NR
MIDIA, before seroconversion interval (146)‡ | 11/144 (7.6%) vs. 25/250 (10.0%) OR 0.75 (0.36–1.57) | NR
VIGR (137)* | 4/59 (6.8%) vs. 6/59 (10.2%) OR 0.6 (0.2–2.4) | NR
EV antibodies in blood
BABYDIAB (143) | 0/62 (0%) vs. NR | 0/28 (0%) vs. NR
DIPP, at least one of 41 EV serotypes (145)§ | NR | NR
DIPP, coxsackievirus B1 (145)§ | NR | 108/183 (59%) vs. 183/366 (50%) OR 1.5 (1.0–2.2)
Combination of methods
Serology and/or serum EV RNA; DIPP (141) | 33/152 (22%) vs. 105/751 (14%) OR 1.7 (1.1–2.6) | NR
Serology and/or serum RNA; TRIGR (152) | NR (0.83 vs. 0.29 infections per child reported significantly different) | NR
EV RNA in rectal swab or saliva; DAISY (144) | 0/17 (0%) vs. 3/35 (9%) | 0/10 (0%) vs. 3/21 (14%)
EV RNA in serum, rectal swab, or saliva; DAISY (relatives) (144) | 1/10 (10%) vs. 2/8 (25%) OR 0.3 (0.02–4.6) | 1/6 (17%) vs. 2/6 (33%) OR 0.4 (0.03–6.2)

CI, confidence interval; DAISY, Diabetes Autoimmunity Study in the Young; DiMe, Childhood Diabetes in Finland Study; DIPP, Diabetes Prediction and Prevention Study; EV, enterovirus; MIDIA, Environmental Triggers of Type 1 Diabetes study; NR, not reported; OR, odds ratio; RNA, ribonucleic acid; TEDDY, The Environmental Determinants of Diabetes in the Young study; TRIGR, Trial to Reduce IDDM in the Genetically at Risk; VIGR, Viruses in the Genetically at Risk study.

* Results for VIGR (137) were reported as frequency of EV in cases and controls being identical (hence “x/32 in both cases and controls, x not reported), but there was suggestive association when analyzed at the species level with Enteroviruses A and B being more frequent in cases than controls, albeit not significantly so; see text. The 32 samples (each for cases and controls) came from 20 subjects. Plasma samples (n=59) came from 41 islet autoimmunity case children.

† Detailed frequencies were not reported for any Enterovirus A–D, but TEDDY reported significant results with increased risk of islet autoimmunity for persistent positivity for Enterovirus B in subgroup analyses; see text.

‡ MIDIA also reported that in the first islet autoantibody positive sample and corresponding time in matched controls, EV RNA tended to be more common in cases (10.5%) than in controls (5.8%); see text.

§ In this analysis from DIPP (145), the authors reported results separately for serum-neutralizing antibodies for each of 41 enterovirus serotypes, of which only coxsackievirus B1 showed nominally significant association with increased risk of islet autoimmunity and coxsackieviruses B3 and B6 showed a nominally significant inverse association; see text.

SOURCE: References are listed within the table.

TABLE 5.

Summary of Studies of the Possible Association Between SARS-Cov-2 Infection or COVID-19 With Subsequent Risk of Type 1 Diabetes in Young Individuals

STUDY PERIOD (REF.) | POPULATION | DESIGN | AGE GROUP(S) | OUTCOME DEFINITION (DIABETES) | LOOK-BACK PERIOD* | EXPOSURE DEFINITION | TOTAL SAMPLE SIZE | N T1D | RESULT (OR, RR, IR, HR)† | COMMENT
March 1, 2020 – February 26, 2021 (160) | U.S. claims database: IQVIA | Matched cohort (exposed vs. nonexposed) | <18 years | ≥1 entry of any type of diabetes in database | Unclear (from 2013?) | >30 days after PCR or clinical COVID-19 diagnosis | ∼7 million | <200 (?) | HR 2.6 (1.98–3.56) | All types of diabetes and too high incidence of diabetes (prevalent cases?). Not adjusted for ethnicity.
March 1, 2020 – June 28, 2021 (160) | U.S. claims database: HealthVerity | Matched cohort PCR test negative | <18 years | ≥1 entry of any type of diabetes in database | Unclear (from 2014?) | >30 days after PCR+ | ∼0.8 million | <1,973 (?) | HR 1.31 (1.20–1.44) | See above.
January 1, 2020 – June 11, 2021 (161) | Commercial, global claims database: TriNetX | Propensity matched within commercial database | 0–18 and 19–30 years | T1D (?), electronic claims data codes | Unclear | ≥1 day after PCR+ or COVID diagnosis vs. not | ∼548,000 in matched analysis (of total ∼4 million) | 122 | Age (years) 0–18 RR 0.87 (0.51–1.47) 19–30 RR 1.87 (1.13–3.11) | Details of database are unclear. (No adjustment for location/ place of residence?)
March 2020 –December 2021 (162) | Commercial, global claims database: TriNetX | Propensity score matched (1:1) cohort | <19 years | T1D, electronic claims data codes | Unclear | Diagnosis of COVID-19 or SARS-CoV-2 PCR+ vs. other respiratory infection | ∼570,000 | 195 | HR (vs. respiratory infection): 6 months after infection: 1.83 (1.36–2.44) | Details of database are unclear. Also results 1 and 3 months after infection. Compared to other respiratory infections.
January 1, 2019 – July 31, 2021 (163) | Commercial, U.S. claims database: Cerner Real-World Data | Propensity score matched cohort | All ages (analyses finely stratified by age groups) | T1D codes (E10.x), but also included O24.x, which is gestational diabetes. | Unclear | ≥1 day after exposure | 27.3 million | Age (years) All >42,000 6–12 2,354 18–35 >10,000 | Age (years) All OR 1.42 6–12 OR 2.04 (1.78–2.33) 18–35 OR 0.97 (0.91–1.04) | Details of database are unclear.
March 1, 2020 – November 22, 2021 (164)‡ | All population of Scotland | Registries cohort | <35 years (subanalyses in ages 0–15 and 16–34 years) | Validated clinical T1D diagnosis in diabetes registry | ≥5 years | ≥30 days after PCR+ vs. not | 1.85 million | 635 | HR 0.86 (0.62–1.21)
March 1, 2020 – August 25, 2022 (165) | All population of Denmark | Registries cohort, plus test negative design | <18 years | ICD-10 codes in the national patient register | Unclear, but likely several years | >30 days after SARS-CoV-2 test | ∼1.1 million | 613 | HR 0.85 (0.70–1.04)
January 2020 – March 2022 (166) | All population of Norway | Registries cohort + test negative design | <18 years§ | ICD-10 T1D codes, plus use of insulin (two independent registries) | Since 2008 | >30 days after SARS-CoV-2 test | ∼1.2 million | 990 | HR 1.63 (1.08–2.47)

ICD-10, International Classification of Diseases, Tenth Revision; PCR, polymerase chain reaction; SARS-CoV-2, severe acute respiratory syndrome coronavirus 2; T1D, type 1 diabetes.

* Time before incident cases of diabetes were counted in which the study could document lack of a previous diabetes diagnosis. A sufficient period (usually at least one year, often more, depending on the health care system) is essential to ensure that the diabetes code/entry/claim used in the analysis represents a truly incident rather than prevalent case of diabetes. For instance, if a patient is in contact with the health care system once every year, then more than one year is necessary to rule out prevalent diabetes. Also, immigration or patients moving between provider/hospital/care provider catchment areas may appear as incident cases unless this is handled in the database.

† Measure of association (HR, hazard ratio; IR, incidence rate ratio; OR, odds ratio; RR, risk ratio) reporting the ratio of risk (or hazard or incidence or odds) of diabetes among those with versus without exposure to coronavirus or COVID-19, with the 95% confidence interval in parentheses.

‡ Published in Diabetes Care in July 2022, but initially published as preprint in February 2022 in medRxiv: https://www.medrxiv.org/content/medrxiv/early/2022/02/11/2022.02.11.22270785.full.pdf

§ Additional unpublished results for age 18–29-year-olds are discussed in the text.

SOURCE: References are listed within the table.

TABLE 6.

Summary of Published Nutritional Findings From Prospective Studies of Islet Autoimmunity and Type 1 Diabetes

NUTRITIONAL EXPOSURE | PREDICTORS OF INCREASED RISK OF ISLET AUTOIMMUNITY (STUDY) (REF.) | PREDICTORS OF RISK OF PROGRESSION TO TYPE 1 DIABETES IN CHILDREN WITH ISLET AUTOIMMUNITY (STUDY) (REF.) | PREDICTORS OF INCREASED RISK OF TYPE 1 DIABETES IN COHORT (STUDY) (REF.)
Maternal diet and in utero nutrient exposures | No association with gluten (or any foods) in maternal diet during pregnancy (TEDDY) (265) | | Higher intake of gluten in the maternal diet during pregnancy (DNBC) (263)
| Low intake of vitamin D from foods in maternal diet during pregnancy (DAISY) (438) | | No association with gluten in maternal diet during pregnancy (MoBa) (264)
| No association with maternal use of vitamin D or omega-3 supplements during pregnancy (TEDDY) (269) | | No association with gluten (or any foods) in maternal diet during pregnancy (TEDDY) (265)
| No association of maternal intake of retinol, beta-carotene, vitamin C, vitamin E, selenium, zinc, or manganese from foods and supplements (DIPP) (268) | | Lower serum 25(OH)D levels in mother during pregnancy (258) No association of 25(OH)D levels in mother during pregnancy (259)
| | | No association of 25(OH)D in pregnancy or newborns (MoBa and DNBC) (260)*
| | | No association of 25(OH)D in newborns (261)
| | | No association of 25(OH)D in newborns (262)
Breastfeeding | No association with longer duration of exclusive or partial breastfeeding (DAISY (273), BABYDIAB (276), TEDDY (281,289), DIPP (279)) | No association with longer duration of exclusive or partial breastfeeding (DIPP) (279) | No association with longer duration of exclusive or partial breastfeeding (MoBa and DNBC (283), DAISY (274), DIPP (279))
| No association with breastfeeding for less than 12 months (MIDIA) (280) | Breastfeeding for less than 12 months (MIDIA) (280) | Breastfeeding for less than 12 months (MIDIA) (280)
| | | Never breastfed (MoBa and DNBC) (283)
| | | Infant not breastfed when first exposed to gluten (DAISY) (274)
Cow’s milk in infant diet* | No effect of cow’s milk-based formula compared with hydrolysate formula in infancy (TRIGR) (287) | | No effect of cow’s milk-based formula compared with hydrolysate formula in infancy (TRIGR) (288)
| Use of hydrolyzed infant formula compared with cow’s milk-based formula (TEDDY) (289)
Cow’s milk in childhood* | Increased childhood cow’s milk consumption (DIPP) (290) | Increased childhood cow’s milk consumption (DAISY) (294)
| Increased serum myristic acid, pentadecanoic acid, monounsaturated palmitoleic acid isomers 16:1 n-7 and 16:1 n-9, and conjugated linoleic acid (biomarkers of milk and ruminant meat fat intake) (DIPP) (439)
Solid foods, cereals, and gluten in infant diet | First exposure to cereals before age 3 months or not until after age 6 months (DAISY) (273) | | First exposure to solid foods before age 4 months or not until after age 6 months (DAISY) (274)
| First exposure to gluten before age 3 months (BABYDIAB) (276) | | First exposure to fruit before age 4 months (DAISY) (274)
| First exposure to gluten between ages 5 and 5.5 months (compared with later), only for islet autoimmunity developing in the first 3 years of life (DIPP) (278) | | First exposure to rice/oat after age 6 months (DAISY) (274)
| Later first exposure to gluten (TEDDY) (281)
| First exposure to root vegetables before age 4 months (DIPP) (278)
| First exposure to egg before age 8 months (compared with after 11 months), only for islet autoimmunity developing in the first 3 years of life (DIPP) (278)
| Environment-environment interaction: Early and late exposure to gluten and increased number of gastrointestinal infections (DAISY) ( 103 )†
Gluten intake in childhood | Higher gluten and fiber intake (DIPP) (303) | | Higher gluten and fiber intake (DIPP) (303)
| No association of gluten intake (DAISY) (304) | No association of gluten intake (DAISY) (304) | Higher gluten intake at age 18 months (MoBa) (264)
Meat intake in childhood | Higher meat intake (DIPP) (440) | | Higher meat intake (DIPP) (440)
Vitamin D intake | No association of vitamin D intake in childhood (DAISY) (307) | No association of vitamin D intake in childhood (DAISY) (307) | No vitamin D supplementation in infancy (NFBC1966) (305)
Vitamin D levels | No association of 25(OH)D in childhood (DAISY (307), DIPP (308)) | No association of 25(OH)D in childhood (DAISY (307), DIPP (308)) | Lower 25(OH)D in childhood (TRIGR) (310)
| Lower 25(OH)D in childhood (TEDDY (309)*, TRIGR (310)) | | Lower 25(OH)D in serum of adult military personnel (311,312)
| | | No association with genetically determined 25(OH)D in Mendelian randomization study (319)
Vitamin E levels | No association with serum α-tocopherol (DIPP) (323) | | Low serum α-tocopherol (322)
Vitamin C levels | Lower plasma ascorbic acid levels (TEDDY) (324) | | No association with plasma ascorbic acid levels (TEDDY) (324)
Polyunsaturated fatty acids intake | Decreased omega-3 fatty acids in diet (DAISY) (326)*
| Lower fish intake (DIPP) (440) | | Lower fish intake (DIPP) (440)
Polyunsaturated fatty acid levels | Decreased erythrocyte membrane omega-3 fatty acid levels (DAISY) (326)
| Lower erythrocyte membrane DPA levels (DAISY) (327)
| Lower serum DHA (DIPP) (295)
| Lower serum ARA:DHA and n-6:n-3 acid ratios (DIPP) (295)
| Lower erythrocyte membrane EPA and DPA in infancy (TEDDY) (328)
| No association with serum omega-3 fatty acids (TRIGR) (329)
Probiotics intake | Later exposure (≥28 days) to probiotics in supplements and formula (TEDDY) (252)*
Sugars/glycemic load intake | No association with sugars or glycemic load/index (DAISY) (339,340) | Higher dietary glycemic index (DAISY) (339)
| | Higher total sugars intake (DAISY) (340)
Body weight, weight gain, obesity, or BMI | Lower weight (DAISY) (353) | | Increased weight gain in infancy (MoBa and DNBC) (350)
| Higher weight (Australian BABYDIAB) (349) | | No association with weight or height z-score (TEDDY) (351)
| Increased BMI z-score (Australian BABYDIAB) (349) | | Increased BMI in childhood (1970 British Birth Cohort) (361)
| Higher weight z-score at age 12 months (TEDDY) (351) | Overweight/obese at age 2–10 years (TRIGR) (362) | Overweight/obese at age 2–10 years (TRIGR) (362)
| Higher weight gain in infancy (TEDDY) (354) | | Increased BMI z-score at ages 7 and 13 years (Copenhagen School Health Records) (363)
Body height and height growth | Lower height (DAISY) (353) | Increased height growth velocity (DAISY) (353)
| Increased height growth velocity (DAISY) (353) | A slower rate of height growth in infancy (TEDDY) (354)
| | Faster rate of height growth in early childhood (TEDDY) (354)

Data in the table include nested case-control studies within prospective cohort studies. 25(OH)D, 25-hydroxy vitamin D; ARA, arachidonic acid; BMI, body mass index; DAISY, Diabetes Autoimmunity Study in the Young; DHA, docosahexaenoic acid; DIPP, Diabetes Prediction and Prevention Study; DNBC, Danish National Birth Cohort; DPA, docosapentaenoic acid; EPA, eicosapentaenoic acid; MIDIA, Environmental Triggers of Type 1 Diabetes study; MoBa, Norwegian Mother, Father and Child Cohort Study; NFBC1966, Northern Finland Birth Cohort; TEDDY, The Environmental Determinants of Diabetes in the Young study; TRIGR, Trial to Reduce IDDM in the Genetically at Risk.

* See also interactions—Table 7.

† Interactions described: gastrointestinal illnesses associated with increased risk of islet autoimmunity, but only among children who were exposed to gluten-containing grains (wheat or barley) either age <4 months or ≥7 months compared with age 4–6 months.

SOURCE: References are listed within the table.

TABLE 7.

Gene-Environment Interactions Reported for Islet Autoimmunity, Progression, or Risk of Type 1 Diabetes

ENVIRONMENTAL EXPOSURE | INTERACTIONS – RISK OF ISLET AUTOIMMUNITY (STUDY) (REF.) | INTERACTIONS – RATE OF PROGRESSION TO TYPE 1 DIABETES IN CHILDREN WITH ISLET AUTOIMMUNITY (STUDY) (REF.) | INTERACTIONS – RISK OF TYPE 1 DIABETES IN COHORT (STUDY) (REF.)
Maternal diet and in utero nutrient exposures | | | Lower 25(OH)D in cord blood (at birth) and VDR (MoBa) ( 430 )
Cow’s milk in infant diet | Early cow’s milk formula exposure and PTPN22 (DIPP) ( 427 )*
Cow’s milk in childhood | Increased childhood cow’s milk consumption and HLA (DAISY) (294)†
Solid foods, cereals, and gluten in infant diet | First exposure to cereals before age 3 months or not until after age 6 months and HLA (DAISY) (273)‡
| First exposure to solid foods at 3–4 months (compared with after 4 months), only in those with the high-risk HLA genotype (DIPP) (279)
Child’s vitamin D levels | Lower 25(OH)D in childhood and VDR (TEDDY) ( 309 )§
Polyunsaturated fatty acids intake in childhood | Decreased ALA intake and FADS1/FADS2 (DAISY) ( 327 )║
Probiotics intake | Later exposure (≥28 days) to probiotics in supplements and formula, only in those with HLA-DR3/4 (TEDDY) (252)
Sugars/glycemic load intake | | More sugar-sweetened beverages and HLA-DR (DAISY) (340)¶

Data in the table include nested case-control studies within prospective cohort studies. 25(OH)D, 25-hydroxy vitamin D; ALA, alpha-linolenic acid; DAISY, Diabetes Autoimmunity Study in the Young; DIPP, Diabetes Prediction and Prevention Study; HLA, human leukocyte antigen; FADS1, delta-5-desaturase gene; FADS2, delta-6-desaturase gene; MoBa, Norwegian Mother, Father and Child Cohort Study; PTPN22, protein tyrosine phosphatase non-receptor type 22 gene; SNP, single nucleotide polymorphism; TEDDY, The Environmental Determinants of Diabetes in the Young study; VDR, vitamin D receptor gene.

* Possessing the PTPN22 polymorphism increases risk only in children exposed to cow’s milk formula during early infancy.

† Increased childhood cow’s milk consumption in the moderate-risk HLA group, not the high-risk group

‡ Early and late exposures to cereals are more strongly associated with islet autoimmunity in children with HLA-DR3/4 genotype compared with those with the moderate- and low-risk HLA-DR genotypes (interaction term was marginally statistically significant).

§ Inverse association between 25(OH)D levels and islet autoimmunity is seen only in those with minor alleles at VDR Apa1 SNP.

║ ALA intake is more protective in the presence of increasing number of minor alleles at FADS1 and FADS2.

¶ Higher intake of sugar-sweetened beverages increases risk of progression from islet autoimmunity to type 1 diabetes, only in those with high-risk HLA genotype.

SOURCE: References are listed within the table.