# Quality of Care in Adults With Diabetes

## Summary

This article reviews the evidence behind current quality metrics and evaluates how well diabetes care in the United States meets high-quality standards at the individual and organizational levels. Clinical recommendations for diabetes focus on managing risk factors to prevent and treat microvascular and macrovascular complications. These clinical recommendations have been the primary source materials for current quality indicators for diabetes care. These indicators include achieving targeted glycemic control (glycated hemoglobin [A1C] levels <7% or <8%), maintaining blood pressure <130/80 or <140/90 mmHg, reaching low-density lipoprotein (LDL) cholesterol levels <100 mg/dL for those without atherosclerotic cardiovascular disease (ASCVD) or <70 mg/dL for those with ASCVD, smoking cessation, annual screenings for eye, kidney, and foot health, and receiving specific immunizations (pneumococcal vaccine and annual influenza vaccine). A composite measure of controlling glycemia, blood pressure, and cholesterol and avoiding tobacco is also used, identifying individuals with control of all four factors.

Since the late 1990s, the population with diagnosed diabetes in the United States has become older, more diverse, and more insured. Risk factor control in people with diabetes in the United States has seen improvements but has plateaued over the last decade. For example, the percentage of individuals achieving A1C levels <8.0% rose from 71.1% in 1999–2004 to 78.6% in 2005–2010 but declined to 75.6% by 2017–2020. Blood pressure control <140/90 mmHg improved from 65.7% to 73.1% from 1999–2004 to 2011–2016, then declined to 71.5% by 2017–2020. Meanwhile, LDL cholesterol management <100 mg/dL without ASCVD or <70 mg/dL in those with ASCVD significantly increased, from 32.3% in 1999–2004 to 56.1% in 2017–2020. Racial and ethnic disparities persist, with non-Hispanic Black and Hispanic individuals less likely to achieve A1C control <8.0% and blood pressure <140/90 mmHg compared to non-Hispanic White individuals. Uninsured individuals are also less likely to achieve risk factor control compared to individuals with insurance, including A1C <8.0%, LDL cholesterol control, and the composite measure of risk factor control. Similarly, younger adults age 20–44 years demonstrate poorer outcomes in glycemic and lipid control, smoking cessation, and composite risk factors compared to older adults. National data highlight a high prevalence of diabetes-related complications, including ASCVD, chronic kidney disease (CKD), and retinopathy. Annual hospitalization rates for diabetes-related discharges have increased over time with notable increases in diabetic ketoacidosis (from 2.15 cases per 100 people in 2000 to 4.15 cases per 100 people in 2020) and hypoglycemia (from 0.08 cases per 100 people in 2000 to 0.57 cases per 100 people in 2020).

This article concludes by identifying key areas for improvement in diabetes quality-of-care measurement. With growing recognition that diabetes varies in phenotypes and severity, there is an emphasis on tailoring quality indicators and thresholds to population subgroups based on risk level. As such, clinical guidelines are beginning to incorporate personalized treatment recommendations based on genetic, clinical, and social factors. Expanding quality-of-care standards to include novel indicators could improve outcomes for individuals and identify system-wide improvements in diabetes care.

## Introduction

Diabetes is an important public health challenge in the United States, affecting 38.1 million adults and placing substantial health and economic burdens on healthcare systems and society (1). With healthcare expenditures consuming approximately 17% of the U.S. gross domestic product—the highest proportion among developed nations—it is critical to examine the quality of care provided to those living with diabetes (2). Despite the extensive resources allocated to healthcare, key health indicators in the United States often lag behind those of other developed nations, raising concerns about the effectiveness, efficiency, and equity of care (3).

Quality of care for people with diabetes is important given the chronic nature of the disease and its associated complications, including atherosclerotic cardiovascular disease (ASCVD), chronic kidney disease (CKD), and retinopathy. As the diabetes population ages and becomes more diverse, the need for rigorous, evidence-based quality metrics becomes increasingly urgent. Traditional clinical guidelines have emphasized controlling blood glucose, blood pressure, and cholesterol, promoting smoking cessation, as well as composite measures of multiple risk factors, and conducting regular preventive screenings for early identification of complications. However, recent data suggest that while there have been improvements in some areas, the overall progress in diabetes management has plateaued, and significant disparities in care persist across different demographic groups.

This article provides a comprehensive review of the current state of diabetes care in the United States, examining both the successes and challenges in meeting established quality standards and updating the Diabetes in America, 3rd edition, chapter Quality of Care in People With Diabetes (3). It also explores the evolution of quality metrics, the impact of healthcare policies, and the ongoing efforts towards personalized care for people with diabetes. By understanding the factors that contribute to high-quality care and identifying areas for improvement, this article aims to inform strategies that can enhance health outcomes for people with diabetes across the nation.

## Sources and Limitations of National Data on Quality of Care in U.S. Adults With Diabetes

Previous studies have leveraged national survey datasets to evaluate the quality of diabetes care at a national level (4,5,6,7,8,9,10,11,12,13,14). In general, diabetes management and related health measures have improved among U.S. adults, with significant increases in the use of blood pressure- and lipid-lowering medications. However, many individuals, particularly in certain demographic groups, still fall short of clinically recommended goals.

De novo analyses were conducted to examine the trends in diabetes care quality across multiple iterations of the National Health and Nutrition Examination Survey (NHANES), the National Health Interview Survey (NHIS), and the Healthcare Cost and Utilization Project National Inpatient Sample (HCUP-NIS). All estimates are age-standardized to the most recent datasets (NHANES, NHIS, HCUP) specific to individuals with diabetes, using age groups 20–44, 45–64, and ≥65 years, except for analyses comparing different age groups, which are not age-standardized. With greater availability of data, these new analyses also provide more in-depth assessments of Hispanic and Asian populations with diabetes in the United States.

Despite the strengths of these national datasets, the NHANES, NHIS, and HCUP do not capture information on medication adherence, which may influence health outcomes and quality-of-care assessments.

### The National Health and Nutrition Examination Survey (NHANES)

The NHANES is a cross-sectional, multistage, stratified, clustered probability sample of the noninstitutionalized civilian population in the United States, conducted by the National Center for Health Statistics, a division of the Centers for Disease Control and Prevention (CDC). Each NHANES survey cycle includes both interview and examination components, including blood collection.

NHANES represents one of the most important sources of information on the nation’s health, providing comprehensive data on diabetes and its associated risk factors within the general U.S. population. Glycated hemoglobin (A1C), blood pressure, low-density lipoprotein (LDL) cholesterol, smoking status, preventive measures, and health behaviors are assessed. Diabetes, cardiovascular diseases, and retinopathy are determined through self-report. Smoking history, eye, dental, and foot examinations, glucose monitoring, physical activity, diet, and healthcare access are also based on self-reported data. The analyses herein are based on combined survey years of continuous NHANES (1999–2020). Since the COVID-19 (coronavirus disease of 2019) pandemic disrupted data collection, data collected from 2019 to March 2020 were merged with data from the NHANES 2017–2018 cycle to form a nationally representative sample of NHANES 2017–March 2020 prepandemic data.

Additionally, to increase precision for these analyses, the NHANES cycles were grouped as 1999–2004, 2005–2010, 2011–2016, and 2017–2020 periods to provide more reliable estimates.

### The National Health Interview Survey (NHIS)

The NHIS is an annual, cross-sectional survey of the noninstitutionalized civilian population in the United States designed to capture nationally representative data on various health topics. It is conducted by the CDC’s National Center for Health Statistics and executed by the U.S. Census Bureau. The NHIS was used to track self-reported vaccination trends among U.S. adults with diabetes from 2000 to 2020.

### The Healthcare Cost and Utilization Project (HCUP)-National Inpatient Sample (NIS)

The NIS, a part of the HCUP sponsored by the Agency for Healthcare Research and Quality (AHRQ), is the U.S. all-payer inpatient healthcare database and offers detailed insights on aspects of inpatient care, including utilization, cost, quality, and outcomes. NIS data were used to monitor hospital admissions related to diabetic complications among U.S. adults with diabetes from 2000 to 2020.

### Statistical Methods

The NHANES and NHIS use complex survey designs with oversampling of some population subgroups to improve survey reliability; therefore, estimates for each survey were weighted separately to produce nationally representative estimates of the noninstitutionalized population in the United States. Data from the HCUP are also weighted to ensure that the estimates accurately reflect the national population of hospital discharges. Weighted standard errors (SE) are provided for estimates in tables, and weighted 95% confidence intervals are provided in some figures. Percent estimates were considered significantly different if 95% confidence intervals prepared with weighted standard errors did not overlap. The relative standard error (RSE = [SE/estimate]*100) is provided in tables and figures for estimates that are likely unreliable due to sample size. Estimates with RSE >50% are censored.

## Quality as a High Priority

Quality healthcare is fundamental to the well-being of any population, especially within the United States where healthcare consumes approximately 17% of gross domestic product—the highest in the world—but health indicators lag behind most peer nations (2,3). To address this imbalance, payers and systems are increasingly embracing value-based (or “pay for quality”) payment models—instead of service-based (or “pay for each service”) models—amidst rising rates of chronic diseases. With an estimated 38.1 million American adults living with diabetes, establishing benchmarks and monitoring quality have become essential to healthcare and public health, as diabetes is a chronic condition with disproportionate economic burdens (1,15).

The commitment to defining and measuring quality of care is shared among patients, clinicians, health systems, communities, and governments, all of whom prioritize reducing the burdens of diseases like diabetes. Developing a universally applicable and actionable definition of diabetes care quality remains a work in progress, as does ensuring that the measures used to assess it effectively drive meaningful improvements in both care and health outcomes.

In 1988, Donabedian identified the multifaceted nature of quality and proposed a model with three core components: structure, process, and outcomes (16). He emphasized that definitions of quality may vary based on the care system and its specific responsibilities (17). In a subsequent effort to provide clarity, the Institute of Medicine (IOM) in 1990 defined quality in healthcare as “the degree to which health services for individuals and populations increase the likelihood of desired health outcomes and are consistent with current professional knowledge” (18).

Building on these perspectives, Blumenthal proposed four perspectives on quality: the healthcare professional perspective, the patient perspective, the perspective of healthcare plans and organizations, and the purchaser perspective (19). Healthcare professionals often perceive quality of care based on the technical proficiency and characteristics of patient-clinician interactions (19). In contrast, patients primarily assess healthcare quality based on their personal preferences and values, emphasizing care satisfaction and tangible health outcomes (19). Healthcare plans emphasize the overall health of their enrollees and organizational functionality, focusing on meeting the broader needs with fixed resources; like health plans, purchasers also prioritize population-based quality measures, both processes and outcomes, as well as value, which they may use to compare alternative health plans (19). In essence, the pursuit of quality in healthcare is a multifaceted endeavor, shaped by a spectrum of viewpoints that collectively strive to optimize patient outcomes and system performance.

The evaluation of quality of care necessitates a multifaceted approach, as exemplified by the IOM’s Six Domains of Health Care Quality, which consider safety, effectiveness, efficiency, patient-centeredness, timeliness, and equity (20). Safety measures protect patients from preventable harm, ensuring that diabetes management does not lead to additional health risks. Effectiveness speaks to the desire to utilize interventions that are supported by data regarding improving health and outcomes. Efficiency and value measures are crucial for balancing the cost of diabetes care with quality and outcomes, aiming to make healthcare more affordable and impactful. Patient-centeredness, timeliness, and equity measures are still in developmental stages but are necessary for ensuring prompt, personalized care that addresses disparities and meets the diverse needs of the diabetes population. These diverse domains underscore the critical importance of a holistic approach to quality.

Defining quality in healthcare involves an intricate balance of varied perspectives, methodologies, and historical contributions. While its multifaceted nature means there is no singular definition, the common thread lies in the quest to achieve optimal outcomes for patients, ensuring that care delivery is effective, efficient, and aligned with both professional standards and patient values.

## Achievements and Challenges of Organization-Level Quality Improvement Initiatives

High-quality diabetes care has been a subject of continuous development and refinement, with its measurement evolving over time (21,22). The necessity for quality healthcare in diabetes and its measurement has become more pressing due to the escalating diabetes prevalence, rising healthcare costs, and the substantial impact of diabetes and related comorbid conditions (e.g., ASCVD, depression, etc.) on patients’ quality of life (1,23).

Amid the different organizational endeavors in the mid-1990s to develop and implement quality metrics, a demand for standardized performance measures arose (24). Responding to this call, the National Diabetes Quality Improvement Project (NDQIP) introduced the first national performance improvement framework in 1997, providing a unified approach to diabetes care quality (21). The initial quality measures, though groundbreaking, had their shortcomings as they lacked evidence for efficacy and had no validated risk-adjustment model. During the early 2000s, the National Committee for Quality Assurance (NCQA) made few changes to the initial threshold values of quality metrics. By the same token, clinical measures, including A1C, blood pressure, and cholesterol targets, were adopted by the Bridges to Excellence pay-for-performance program from the NCQA (25,26).

Advancements were not merely confined to isolated measures but included composite metrics as well. The Minnesota Community Measurement Diabetes 5 (MNCM D5) measure, for instance, is a composite measure, a confluence of clinical and behavioral measures that includes: A1C, blood pressure, LDL cholesterol, administration of aspirin among those with a history of ASCVD, and nonsmoking status (27). Since 2010, the Minnesota Project has required clinicians to submit clinical data and has made a summary of this data accessible to the community (27).

Currently, several organizations, including NCQA’s Healthcare Effectiveness Data and Information Set (HEDIS), Medicaid Adult Health Care Quality Measures, Medicare Five-Star Quality Rating System, and the Consumer Assessment of Health Providers and Systems, offer diabetes quality metrics, contributing to an elaborate landscape of quality measurement. In addition to these collaborative efforts, the National Clinical Care Commission (NCCC), established by the U.S. Congress in 2017, was tasked to evaluate and improve federal programs for diabetes. The NCCC’s 2022 report outlined key recommendations to enhance diabetes care delivery (28,29). These recommendations included updating the 2000 Medicare Quality Standards for diabetes self-management training, establishing a regular review process to ensure eligibility, documentation, and reimbursement criteria are transparent and uniformly applied. The NCCC also advocated the introduction of a new quality measure aimed at monitoring and preventing overtreatment, inappropriate treatment, or the risk of severe hypoglycemia in Medicare beneficiaries with diabetes, especially those with life-limiting conditions. Additionally, the NCCC recommended the development of measures to assess screening for prediabetes and referral to prevention programs, emphasizing the importance of early detection and prevention in diabetes care. These measures aim to enhance patient safety and care quality for this vulnerable group.

Despite the progress and improvements made in quality of diabetes care measures, challenges remain. Existing quality measures have limitations, such as the alignment between surrogate outcomes and hard health outcomes (i.e., diabetes complications that are associated with morbidity and mortality). Also, even the group of current quality indicators, either threshold measures or dichotomous measures, do not fully encapsulate all aspects of quality of care. This is partly because some evidence-based recommendations are supported by surrogate outcomes rather than directly by hard clinical outcomes (30,31). Additionally, these measures do not provide a solution for inappropriate treatment. These challenges, along with the continuous evolution of diabetes care, underscore the need for improved quality care measures to enhance effectiveness, efficiency, and equity in the management of this complex disease.

## The Evidence Base for Definitions of Quality-of-Care Metrics in Diabetes

Quality metrics in diabetes care currently focus on effectiveness, ensuring that individuals with diabetes receive comprehensive, evidence-based care that can help manage the disease and prevent complications. These quality metrics often serve as benchmarks to assess the performance of healthcare professionals and systems, and they must also be feasible to evaluate using administrative or claims data. Current metrics include A1C testing, A1C levels for both “poor” control (>9.0% [>75 mmol/mol]) and “good” control (either <8.0% [<64 mmol/mol] or <7.0% [<53 mmol/mol] in some cases), blood pressure control (<140/90 mmHg or <130/80 mmHg), lipid control (LDL cholesterol <100 mg/dL [<2.59 mmol/L] without preexisting ASCVD or <70 mg/dL [<1.81 mmol/L] if a person has preexisting ASCVD), annual eye and foot examinations, annual medical evaluation for nephropathy, avoiding tobacco, and receiving specific immunizations (one-time pneumococcal vaccine prior to age 65 years and annual influenza vaccine). A composite measure of controlling glycemia, blood pressure, and cholesterol and avoiding tobacco is also used (21,27,32,33).

A1C has been the primary measure for assessing glycemic management. Previously, the American Diabetes Association (ADA) and others advised keeping A1C levels ≤7.0% based on evidence from clinical trials showing reductions in microvascular complications (34,35,36,37,38,39). The 1993 Diabetes Control and Complications Trial (DCCT) for type 1 diabetes showed significant reductions in microvascular diseases in patients with A1C levels <7.0% compared to those treated more conventionally (A1C >9.0%) (35). For type 2 diabetes, the recommendation to maintain A1C ≤7.0% originated from the United Kingdom Prospective Diabetes Study (UKPDS) (36,37). This study highlighted significant reductions in microvascular complications (25% relative risk reduction for combined microvascular outcomes, p<0.01). Additionally, there was a modest, statistically nonsignificant decline in the risk of myocardial infarction (MI) with improved glycemic control, showing a 16% relative risk reduction (p=0.052) among adults with newly diagnosed type 2 diabetes. Long-lasting advantages of glycemic control for both small and large vessel diseases have been observed in extended follow-ups of both DCCT and UKPDS participants (40,41,42,43,44). Notably, these studies were conducted before the widespread use of statins and in an era where strict blood pressure management was not a central aspect of routine diabetes care.

Trial evidence regarding the risks of pursuing A1C levels <7.0% have since been hotly debated. Observational data showed a direct relationship between higher A1C levels and poor outcomes (45). However, the Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation (ADVANCE) and the Veterans Affairs Diabetes Trial (VADT) were randomized trials that showed very intensive glycemic control (e.g., A1C <6.5% [<48 mmol/mol]) with medications available at the time (insulin, sulfonylureas, thiazolidinediones) in older adults with diabetes produced only modest cardiovascular benefits (46,47,48). In the case of the Action to Control Cardiovascular Risk in Diabetes (ACCORD), which primarily utilized insulin, thiazolidinediones (specifically rosiglitazone) and sulfonylureas posed potential harms (49,50). These trials reinforced the idea that while glucose control is vital, glycemic targets need to be individualized based on patients’ risks and benefits (47,51,52). While A1C <7% has commonly been a target for glycemic control, most composite measures in diabetes care recommend an A1C threshold of <8%, as not all patients are well-suited for an A1C goal of <7%. This approach helps avoid incentivizing overtreatment, particularly in individuals for whom lower targets might pose risks.

Current blood pressure management recommendations in people with diabetes emphasize a personalized approach to setting blood pressure targets, considering cardiovascular risk and potential side effects from antihypertensive medications (53,54,55). This recognizes that the benefits and risks of intensive blood pressure targets are uncertain, and clinical characteristics can help determine whether an individual will benefit from intense blood pressure control with minimum threshold blood pressure control of <140/90 mmHg (49,56,57,58,59,60,61,62,63,64,65). It is noteworthy that 2024 ADA clinical practice guidelines revised the blood pressure control recommendations to a more stringent target of <130/80 mmHg (66). This revision, which aligns with guidelines from the American College of Cardiology (ACC) and the American Heart Association (AHA), also acknowledges the controversy arising from differing evidence between trials involving individuals with and without diabetes (66). Broad evidence, including findings from the Systolic Blood Pressure Intervention Trial (SPRINT), supports a systolic blood pressure <120 mmHg target to reduce cardiovascular events in high-risk groups, though the trial did not include participants with diabetes. Diabetes-specific trials like the ACCORD blood pressure trial revealed no significant impact of a target systolic blood pressure <120 mmHg on composite cardiovascular endpoints, although a decrease in stroke risk was observed (49,67). Thus, the guidelines advocate individualized treatment goals, factoring in the patient’s overall cardiovascular risk profile, potential for benefit, and risk of adverse effects from intensive blood pressure management.

The ADA advocates for annual cholesterol screenings for those with diabetes, and use of moderate-intensity statins is encouraged in individuals with diabetes age 40–75 years who do not have ASCVD (68). Since 2023, the target for LDL cholesterol has been lowered to <70 mg/dL for those with an ASCVD risk factor and <55 mg/dL (<1.42 mmol/L) for those with ASCVD (53,69). These recommendations are supported by numerous clinical trials that have demonstrated significant primary and secondary prevention benefits of ASCVD with statin therapy in individuals with diabetes (70,71,72,73). ACC/AHA guidelines also recommend maintaining LDL cholesterol levels <55 mg/dL for individuals with very high risk (74,75). These evolving recommendations reflect ongoing discussions about the most effective LDL targets for cardiovascular protection in high-risk patients, with evidence supporting both thresholds depending on individual patient risk profiles.

The evidence for the benefits of comprehensive multi-risk factor control is available from STENO-2. The STENO-2 trial in Denmark showed that comprehensive attention to A1C, blood pressure, cholesterol, and use of statins and angiotensin receptor-modifying agents was associated with remarkable reductions in cardiovascular events and mortality compared to standard care (76,77). Thus, glycemic control and nonglycemic risk factors comprise the focus of macrovascular risk reduction strategies in diabetes.

Aspirin also reduces morbidity and mortality from ASCVD in individuals with a previous history of MI or stroke and is strongly recommended for those individuals (68,78). However, its benefit in primary prevention for people with diabetes who have no prior history of ASCVD is counterbalanced by higher bleeding risk (78).

Over the years, the treatment paradigm for diabetes has substantially evolved owing to breakthroughs in drug development, insights into disease progression, and landmark clinical trials investigating the impact of medications like angiotensin-converting enzyme inhibitors (ACEi), angiotensin II receptor blockers (ARBs), sodium-glucose cotransporter-2 (SGLT2) inhibitors, and glucagon-like peptide-1 (GLP-1) receptor agonists and dual agonists on cardiovascular and renal outcomes.

Contemporary guidelines advocate for use of SGLT2 inhibitors, supported by such trials as Empagliflozin, Cardiovascular Outcomes, and Mortality in Type 2 Diabetes (EMPA-REG OUTCOME), Canagliflozin Cardiovascular Assessment Study (CANVAS), Dapagliflozin in Patients with Chronic Kidney Disease (DAPA-HF and DAPA-CKD), and Canagliflozin and Renal Outcomes in Type 2 Diabetes and Nephropathy (CREDENCE), in patients with type 2 diabetes and either established ASCVD, heart failure, or CKD due to their efficacy in slowing CKD progression and cardiovascular events (79,80,81,82,83,84,85). GLP-1 receptor agonists reduce the risk of major adverse cardiovascular events, all-cause mortality, hospital admissions for heart failure, and worsening kidney function in patients with type 2 diabetes. These agents are also associated with 5%–15% weight reduction among users (86,87,88). They are recommended in patients with type 2 diabetes and established ASCVD or high risk for cardiovascular events (89,90,91,92). The American College of Physicians (ACP) guidelines recommend prioritizing SGLT2 inhibitors or GLP-1 receptor agonists over dipeptidyl peptidase-4 (DPP-4) inhibitors and sulfonylureas due to their superior cardiovascular benefits (93,94). Recent comparative effectiveness studies further support these findings by showing unfavorable cardiovascular outcomes associated with sulfonylureas and DPP-4 inhibitors (95,96,97). Emerging medications, such as tirzepatide, a dual GLP-1 receptor agonist and glucose-dependent insulinotropic polypeptide (GIP) agonist, have demonstrated significant clinical efficacy in glycemic control, weight loss, and improvement of several cardiovascular risk factors, making them promising additions to diabetes care (86,98,99). The Finerenone in Reducing Kidney Failure and Disease Progression in Diabetic Kidney Disease (FIDELIO-DKD) trial findings on nonsteroidal mineralocorticoid receptor antagonists (MRA) establish their potential benefits for patients with specific estimated glomerular filtration rate (eGFR) thresholds (100). While these agents are now part of care guideline recommendations and are expected to enhance quality care by improving cardiovascular and renal outcomes, they are not yet standardized elements of diabetes quality-of-care measurements. Furthermore, the impact of these medications on quality of care in diabetes is still largely unknown.

Metabolic bariatric surgery has demonstrated significant effectiveness in managing diabetes, with substantial improvements in diabetes remission, glycemic control, and reduction of cardiovascular and renal outcomes. The 2024 ADA guidelines recommend metabolic surgery for individuals with type 2 diabetes and a body mass index (BMI) ≥30 kg/m^2^ (or ≥27.5 kg/m^2^ for Asian American individuals) who are surgically eligible (101). The STAMPEDE trial highlighted that 29% of participants treated with Roux-en-Y gastric bypass (RYGB) and 23% treated with vertical sleeve gastrectomy (VSG) achieved an A1C ≤6.0% (≤42 mmol/mol) after 5 years, significantly surpassing those receiving only medical treatment (102). The ARMMS-T2D study further demonstrated the superiority of metabolic surgery, with 37.5% of participants achieving diabetes remission at 3 years, compared to only 2.6% in the medical/lifestyle intervention group. In addition, this study showed greater reductions in A1C, fasting glucose, and BMI in the surgery group (103). A 10-year follow-up study by Mingrone et al. reinforced the long-term benefits of metabolic surgery, showing that 50% of patients who underwent biliopancreatic diversion (BPD) and 25% of those who had RYGB maintained diabetes remission compared to just 5.5% in the medical therapy group (104). These trials underscore the lasting impact of metabolic surgery on diabetes remission and glycemic control, positioning it as a crucial option for diabetes management.

The overarching clinical guidelines for managing risk factors in diabetes, which target prevention of both microvascular and macrovascular complications, predominantly set the standard for what is considered high-quality care for individuals with diabetes. This approach still emphasizes glucose control, blood pressure regulation, lipid management, and the use of medications with proven cardiovascular and renal benefits. All of these clinical guidelines are reinforced by lifestyle modifications, tobacco avoidance, annual screening for retinopathy, lower extremity neuropathy, and nephropathy to reduce diabetes complications, immunizations, and comprehensive diabetes self-management education and support.

## Quality-of-Care Measures in U.S. National Data, 1999–2020

### Trends in Characteristics of Adults With Diagnosed Diabetes

From 1999 to 2020, the characteristics of people with diagnosed diabetes in the United States have seen substantial shifts (Tables 1 and 2). The prevalence of diagnosed diabetes increased from 11.7% in 1999–2004 to 17.6% in 2017–2020 (Table 1). Among age groups, adults age 20–44 years had the smallest increase, rising from 2.2% to 3.1%, while those age ≥65 years experienced a substantial increase from 16.5% to 24.2%. Across race and ethnicity groups, Mexican American individuals had the largest increase, from 19.0% to 27.6%, and non-Hispanic White and non-Hispanic Black individuals had smaller increases, from 10.0% to 15.4% and 19.2% to 22.8%, respectively. Insurance status also showed notable trends; the prevalence of diagnosed diabetes rose among uninsured individuals from 12.4% to 19.1%, and among those with Medicaid, it increased from 22.2% to 26.5%.

The mean age of people with diabetes increased from 59.2 years in 1999–2004 to 61.1 years in 2017–2020, indicative of an aging population (Table 2). Among people with diagnosed diabetes, the prevalence of those with a disease duration of ≥15 years increased from 28.8% in 1999–2004 to 36.0% in 2017–2020. Conversely, the proportion diagnosed within the last 0–<5 years declined from 36.3% to 25.7% during the same period, indicating a possible saturation of new diagnoses and that more people are living longer with diabetes.

The distribution by sex shows that men account for a greater proportion of those with diagnosed diabetes, rising from 48.3% to 53.8% over two decades. Non-Hispanic White people continue to account for most people with diabetes, although Hispanic people and non-Hispanic Asian people are now both recognized as high-risk groups with substantially higher diabetes prevalence than non-Hispanic White people. The prevalence of overweight and obesity (defined as BMI 25.0–29.9 and ≥30 kg/m^2^, respectively) among individuals with diabetes increased from 83.4% in 1999–2004 to 89.8% in 2017–2020, while the mean BMI rose from 32.0 to 33.1 kg/m^2^ over the same period. Meanwhile, insurance coverage steadily increased among people with diabetes from 89.7% to 93.4%, with notable increases in the percentages of people covered by Medicaid or Medicare.

### Trends in Risk Factor Control Among Adults With Diagnosed Diabetes

From 1999 to 2020, people with diagnosed diabetes in the United States experienced improvements in glycemic control (A1C levels), blood pressure, lipid levels, and smoking cessation (Figure 1, Table 3, Appendix Table A1). Following initial improvements during the first decade, progress has plateaued. More than seventy percent of individuals with diabetes in 2017–2020 still failed to achieve target control based on a composite measure of quality encompassing all three cardiometabolic indicators. Many areas, such as preventive screening completion and health behavior measures, failed to meet the standards necessary for achieving ideal quality care in diabetes management.

The percentage of people with an A1C level >9.0% decreased from 15.2% in 1999–2004 to 12.9% in 2017–2020, while those with an A1C level <8.0% increased from 71.1% to 78.6% in 2005–2010 with subsequent regression to 75.6% in 2017–2020 (Figure 1, Table 3). Similarly, the percentage of individuals maintaining an A1C level <7.0% rose from 49.6% to 54.4% in 2005–2010, then decreased to 52.7% in 2017–2020 (Figure 1, Table 3).

The same pattern of initial improvement followed by regression was observed with the blood pressure threshold of 130/80 mmHg, as well as that of 140/90 mmHg. The proportion of individuals with a level <130/80 mmHg increased from 41.2% in 1999–2004 to 49.2% in 2011–2016 but then decreased to 47.6% in 2017–2020 (Figure 1, Table 3). Using a less stringent goal of <140/90 mmHg, the corresponding percentages were 65.7% in 1999–2004 to 73.1% in 2011–2016 then 71.5% in 2017–2020 (Figure 1, Table 3).

The percentage of people with an LDL cholesterol level <100 mg/dL without ASCVD or <70 mg/dL with ASCVD has considerably improved, rising steadily from 32.3% in 1999–2004 to 56.1% in 2017–2020 (Figure 1, Table 3).

Smoking status among people with diagnosed diabetes showed a positive trend with the percentage of current smokers decreasing from 18.8% in 1999–2004 to 14.6% in 2017–2020, while the rates of never smokers and former smokers have stayed relatively constant (Figure 1, Table 3).

The composite measure of achievement of A1C, blood pressure, LDL cholesterol, and nonsmoking status improved from 13.2% in 1999–2004 to 25.3% in 2017–2020, suggesting better overall risk management (Figure 1, Table 3). However, about three out of four (74.7%) individuals with diabetes still did not reach the ideal goals for this composite measure.

From 1999 to 2020, there has been some improvement in adherence with preventive and health behavior measures. While lipid testing has plateaued over the past decade, there has been a steady improvement in annual eye, dental, and foot exams. Self-monitoring of glucose reached 61.8% in 2011–2016 but declined to 57.1% in 2017–2020 (Table 3). The practice of weight control steadily increased from 41.4% to 46.5% in the last period. However, those who reported adhering to a diabetic diet decreased, moving from 62.6% in 2005–2010 to 57.5% in 2017–2020 (Table 3).

Healthcare utilization for diabetes management has remained stable, with a consistent majority—over 90%—of individuals with diabetes engaging with healthcare services more than once in the past year (Table 3). This consistent utilization spanned from 1999 through 2020, although there has been a slight decrease in recent years.

From 2000 to 2020, there has been a steady increase in annual influenza and in recommended pneumococcal vaccination rates among U.S. adults with diagnosed diabetes (Table 4, Appendix Table A2). These trends suggest a growing awareness and adoption of preventive measures, specifically vaccinations, among people with diabetes over the past two decades. However, approximately 40%–50% of these individuals are still not receiving recommended vaccinations.

### Trends in Medication Use Among Adults With Diagnosed Diabetes

Between 1999 and 2020, diabetes treatment trends in the United States have evolved. The use of any glucose-lowering medication increased from 75.7% in 1999–2004 to 83.3% in 2011–2016 and then leveled off in 2017–2020 (Figure 2, Table 5). There was an increase in the use of insulin, metformin, and newer agents (e.g., SGLT2 inhibitors, GLP-1 receptor agonists, and DPP-4 inhibitors); however, the uptake of these newer medications has been small overall. The use of sulfonylureas and thiazolidinediones has steadily declined.

There has been a gradual increase in U.S. adults with diagnosed diabetes using insulin-only therapy across all age groups (Table 6). This trend could suggest the possibility of an increase in the incidence of type 1 diabetes or an increase in the recognition and diagnosis of adult-onset type 1 diabetes, also known as Latent Autoimmune Diabetes in Adults (LADA). The rising use of insulin-only therapy could also be due to the increase in the population of individuals living with type 2 diabetes for longer periods of time, which is associated with a decline in beta cell function that can only be treated with insulin supplementation.

The patterns of medication usage for managing blood pressure and lipids have similarly changed. The use of any blood pressure-lowering medication increased by 10% from 1999 to 2016 before it plateaued (Figure 2, Table 5). Specifically, the use of ACEi or ARBs and beta blockers increased, while the utilization of calcium channel blockers (CCBs) remained consistently around 20% (Figure 2, Table 5). For lipid management, statin use among adults age ≥40 years rose significantly, contributing to an overall rise in the use of any lipid-lowering medication from 36.2% in 1999–2004 to 60.7% by 2017–2020 (Figure 2, Table 5).

In examining medication trends based on comorbidities from 1999 to 2020, there was an increase in the use of certain medications for patients with specific conditions (Table 7). Among patients with ASCVD, the usage of aspirin or other antiplatelet drugs significantly increased, rising from 44.5% in 1999–2004 to 80.7% in 2017–2020. Use of GLP-1 receptor agonists (1.3% in 2005–2010 to 4.2% in 2017–2020) and SGLT2 inhibitors (0.8% in 2011–2016 to 9.2% in 2017–2020) also increased in this subgroup. Similarly, in those with CKD, the use of ACEi or ARBs rose. Additionally, GLP-1 receptor agonist use increased among individuals with a BMI ≥27.0 kg/m^2^ (Table 7).

These changes over two decades reflect shifts in clinical practice guidelines, the introduction of new therapeutic options, and heightened awareness of the importance of managing broader cardiovascular, renal, and other diabetes-related conditions. Despite these advances, potential gaps remain in the adoption of recommended treatments. An estimated 83.1% of adults with diabetes were using glucose-lowering medications, 58.3% were using ACEi or ARBs, and 59.4% were taking statins in 2017–2020 (Figure 2, Table 5). However, not all individuals with diabetes require medications for every component of ABC care (A1C control, blood pressure management, cholesterol management), and preferences regarding the choice of medications vary.

### Trends in Complications and Hospitalizations Among Adults With Diagnosed Diabetes

Between 1999 and 2020, trends in the prevalence of end-organ complication rates show more declines for microvascular than cardiovascular complications (Figure 3, Table 8). Overall, the prevalence of any self-reported cardiovascular disease remained stable, ranging from 25.1% in 1999–2004 to 25.7% in 2017–2020 (Figure 3, Table 8). The prevalence of coronary heart disease decreased from 13.3% in 1999–2004 to 12.3% in 2011–2016 but increased to 14.8% in 2017–2020. Congestive heart failure prevalence decreased from 11.2% in 1999–2004 to 9.6% in 2017–2020. In contrast, the prevalence of stroke initially rose from 8.8% in 1999–2004 to 11.2% in 2005–2010, followed by a decline to 8.9% in 2011–2016, and a subsequent increase to 10.9% in 2017–2020. The prevalence of any chronic kidney disease (includes eGRF <60 mL/min/1.73 m^2^ or urine albumin to creatinine ratio [ACR] ≥300 mg/mmol) declined from 25.1% to 20.8%. These gains were driven by declines in albuminuria (8.8% to 6.9%) and reductions in the prevalence of low eGFR (<30 mL/min/1.73 m^2^) from 2.6% to 1.8%, as well as declines in moderate CKD (eGFR <60 mL/min/1.73 m^2^) from 19.6% to 16.3%. The prevalence of self-reported retinopathy decreased from 25.1% to 19.6% from 1999–2004 to 2017–2020.

Hospital inpatient discharges for diabetes-related complications increased over time for several important outcomes (Figure 4, Table 9). Approximately 1 per 100 people with diabetes have a hospitalization in a given year for lower extremity amputations. This rate declined to 0.61 per 100 people in 2010 but then returned to 1.30 per 100 people by 2020. Acute metabolic complications, such as diabetic ketoacidosis, hyperosmolar hyperglycemic syndrome, and hypoglycemia, became more frequent from 2000 to 2020. The highest rates were observed for diabetic ketoacidosis, where the rates doubled from 2.15 to 4.15 per 100 people.

### Age Group Differences in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures

Younger and older adults living with diabetes have distinct risk factor control, adherence to preventive measures, and health behavior measure trends (Figure 5, Table 10).

Younger adults (age 20–44 years) with diagnosed diabetes consistently exhibited poorer glycemic and lipid management, higher use of tobacco, and lower achievement of the composite measure of multiple risk factor control compared to their older counterparts (Figure 5, Table 10). For example, in 2017–2020, only 14.3% of the 20–44-years age group achieved multiple risk factor control compared to 20.0% for the 45–64-years age group and 33.5% for the ≥65-years age group.

For the 45–64-years age group, A1C control (from 65.1% to 70.2%) and blood pressure control (from 74.0% to 73.2%) remained stable between 1999 and 2020. LDL cholesterol control showed significant improvement, rising from 27.6% to 51.7%. The percentage of self-reported nonsmokers increased from 74.0% to 80.2%, and composite measure achievement increased from 10.4% in 1999–2004 to 20.0% in 2017–2020 (Figure 5, Table 10).

The ≥65-years age group had steady improvements in multiple domains of diabetes care over the two decades. They generally had the highest levels of control for A1C <8.0%, LDL cholesterol level, and smoking status across age groups, while they have the lowest levels of blood pressure control, at 66.5% in 2017–2020 compared to 83.5% for the youngest age group.

Rates of lipid screenings and annual eye, dental, and foot exams improved across all age groups over the period (Table 10). Both annual influenza and recommended pneumococcal vaccination rates improved over time across all age groups (Table 11).

### Racial and Ethnic Differences in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures

The overall trajectory from 1999 to 2020 indicates improvements in risk factor control across the overall diabetes population in the United States; however, important disparities across racial/ethnic groups persist (Figure 6, Table 12). For A1C, Hispanic adults had the lowest levels of control with minimal improvement over the period. For blood pressure, non-Hispanic Black adults have the lowest levels of control compared to all other groups, a disparity that has been progressively widening. LDL cholesterol control generally improved over time for all groups.

Over the study period, non-Hispanic White adults exhibited relatively stable A1C <8.0% glycemic control (from 74.4% to 78.7%), improved <140/90 mmHg blood pressure control (from 68.6% to 73.3%), and significant progress in LDL cholesterol control (from 33.4% to 56.8%) (Figure 6, Table 12). Self-reported nonsmoking rates improved from 81.9% to 85.0%. Higher influenza vaccination rates were achieved from 56.9% in 2000 to 67.6% in 2020 (Table 13). Pneumococcal vaccine rates improved (from 47.3% to 59.9%) (Table 13), and preventive screenings like annual eye and foot examinations showed overall improvement (Table 12).

Non-Hispanic Black adults exhibited smaller improvements in glycemic control (from 65.3% to 67.5%), achievement of the composite measure of multiple risk factors (from 14.1% to 15.1%), and higher use of tobacco (from 21.7% to 19.3%) compared to all other groups (Figure 6, Table 12). They also experienced a significant decline in blood pressure control (from 62.4% in 2011–2016 to 54.5% in 2017–2020). Influenza vaccination rates rose significantly (from 47.3% to 58.2%), and pneumococcal vaccination rates increased (from 32.7% to 49.1%) (Table 13). However, there were declines in preventive screenings in 2017–2020 compared to prior years (Table 12).

Hispanic adults had no improvement in glycemic control, among the racial and ethnic groups, with the percentage achieving an A1C <8.0% remaining unchanged from 66.0% to 64.4% (Figure 6, Table 12). However, other measures of diabetes care quality improved. Blood pressure control improved from 65.9% to 69.7%. LDL cholesterol control improved from 24.5% to 54.8%. Nonsmoking rates increased significantly from 80.9% to 91.1%. Influenza vaccination rates showed little change, increasing from 45.7% to 55.0%, with Mexican American adults’ rates rising to 54.2%; pneumococcal vaccination rates increased but then declined to 36.6%, with Mexican American adults’ rates achieving 36.1% (Table 13). Preventive screenings and health measures showed overall improvement (Table 12).

Non-Hispanic Asian adults improved in A1C control, with rates increasing from 80.2% in 2011–2016 to 81.6% in 2017–2020 (Figure 6, Table 12). Blood pressure control consistently remained high, ranging from 75.8% to 76.3% during the study period. Lipid control was estimated to increase from 41.7% in 2011–2016 to 52.2% in 2017–2020, though this difference falls within the standard error and should be interpreted with caution. Self-reported nonsmoking rates decreased from 95.1% in 2011–2016 to 93.6% in 2017–2020. Influenza vaccination rates had the most significant improvement, rising sharply from 43.0% to 61.9% from 2000 to 2020; conversely, pneumococcal vaccination rates decreased from 42.9% in 2000 to 34.9% in 2020 (Table 13).

### Insurance Status-Based Trends in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures

As noted earlier, there have been substantial shifts in the insurance status of people living with diabetes, with more having insurance over time, particularly through Medicaid and Medicare. More than 93% of individuals with diabetes had insurance coverage during the 2017–2020 period (105). Among all uninsured adults age ≥20 years, the prevalence of diagnosed diabetes increased from 12.4% in 1999–2004 to 19.1% in 2017–2020. Among all adults with insurance, the prevalence of diabetes increased from 11.6% to 17.8% (Table 14). The major differences in diabetes care quality by health insurance status are observed for those without insurance compared to those with insurance. Among those with insurance, the most important deficits in diabetes care quality are seen in people with Medicaid.

Individuals with diagnosed diabetes without insurance, compared to their insured counterparts, had poorer A1C control (from 56.3% to 69.4%), lipid control (from 40.1% to 14.4%), lower rates of lipid screening, annual eye, dental, and foot exams, as well as lower annual influenza and pneumococcal vaccination rates, compared to their insured counterparts (Figure 7, Tables 15 and 16). For blood pressure control (<140/90 mmHg), the observed differences between uninsured and insured individuals are not statistically reliable.

For those with any insurance, improvements were observed in A1C control (from 72.5% to 76.6%), blood pressure control (from 67.0% to 71.3%), lipid control (from 32.7% to 57.8%), and nonsmoking rates (from 82.3% to 85.8%). The composite measure of multiple risk factors also improved from 13.9% to 25.9%.

Among the insured group, Medicaid recipients exhibited poorer individual and composite risk factor control compared to other insured groups (Figure 8, Tables 15 and 16). A1C control improved over time from 66.4% to 73.2%. Blood pressure control improved from 61.5% to 70.4% in 2011–2016 but then declined to 63.8% in 2017–2020. LDL cholesterol control improved steadily from 32.0% to 50.5%. Self-reported nonsmoking rates increased from 76.0% to 76.6%. Overall, the achievement of the composite measure of multiple risk factors remained low, consistently remaining below 20%. Medicaid recipients had the greatest gaps in preventive screenings, annual health checks, health behavior monitoring, and vaccinations.

Individuals with Medicare/Medi-Gap (Medi-Gap refers to a private insurance policy designed to cover out-of-pocket costs not covered by Original Medicare) generally achieved better control of individual risk factors, composite measures of multiple risk factors, and higher rates of preventive screenings, annual health checks, health behavior monitoring, and vaccinations (Figure 8, Tables 15 and 16).

Among those with Medicare/Medi-Gap, A1C control showed an initial increase but later declined (from 74.5% to 74.2%). Blood pressure control improved steadily over time (from 67.3% to 75.3%). LDL cholesterol control demonstrated significant improvement (from 28.6% to 59.8%). The percentage of self-reported nonsmokers increased initially but slightly declined towards the end (from 78.6% to 77.3%). The achievement of the composite measure of multiple risk factors improved significantly (from 7.9% to 23.7%). Those with Medicare/Medi-Gap coverage saw the most significant increase in influenza vaccination rates, rising from 63.8% to 68.2%. This improvement demonstrates the success of targeted vaccination programs and may also be attributed to age eligibility criteria and the incentivizing impact of quality measures under the Medicare Incentive Payment System (MIPS) within this demographic.

The private insurance group had overall consistent and positive trends in glycemic, blood pressure, and lipid control, as well as health measures, preventive screenings, and vaccinations (Figure 8, Tables 15 and 16). A1C control in the private insurance group showed an overall improvement, rising from 73.1% in 1999–2004 to 77.0% in 2017–2020. Blood pressure control peaked at 76.0% in 2011–2016 but slightly declined to 69.2% in 2017–2020. LDL cholesterol control showed significant improvement, rising from 32.7% in 1999–2004 to 59.3% in 2017–2020. The percentage of self-reported nonsmokers increased from 84.6% to 89.3%, and composite measure achievement improved from 15.8% in 1999–2004 to 23.0% in 2017–2020. Preventive screenings and annual exams showed high adherence, particularly for lipid testing and foot exams, while vaccination rates for influenza and pneumococcal vaccines generally improved, indicating good adherence to preventive care measures.

Other insurance includes state-sponsored plans or other government plans (Figure 8, Tables 15 and 16). For those with other insurance, A1C control varied, peaking at 80.6% in 2005–2010 before declining to 78.2% in 2017–2020. Blood pressure control remained relatively stable, with improvements in LDL cholesterol control and nonsmoking rates. However, given the heterogeneous nature of individuals within the other insurance group, the importance of these findings requires further investigation.

## Discussion

The data from 1999 to 2020 provide a comprehensive view of the quality of diabetes care in the United States, revealing the challenges and variations in risk factor control, preventive screenings, and health behavior measures among adults with diabetes. Despite initial improvements in risk factor control over 1999–2010, large proportions of adults with diabetes are still not meeting guideline-recommended care goals. Over the past decade, the collective impact of quality improvement initiatives in glycemic control, blood pressure, and lipid control, as well as smoking cessation, appears to have plateaued.

Suboptimal medical treatment has been suggested as a contributing factor to the stagnation in diabetes management since 2010, with declines observed in the use of glucose-lowering, blood pressure-lowering, and lipid-lowering medications (6). Consistent with this hypothesis, our study found that rates of medication use to manage comorbid conditions in patients with diabetes remain low. Furthermore, poor medication adherence may explain the worsening of diabetes-related complications. For instance, a cross-sectional study of data from 2005–2019 found that, on average, 19.5% of adults with diabetes did not consistently use glucose-lowering medications (106). Among those individuals with an indication for blood pressure- or lipid-lowering medications, 17.1% and 43.3%, respectively, did not maintain continuity in medication use (106). Other studies report high discontinuation rates of newer medications; 47.7% of adults with type 2 diabetes discontinued GLP-1 receptor agonists (107) and 38.2% discontinued SGLT2 inhibitors over a 12-month period (108). These issues arise from multiple factors, including patient-level barriers, such as adverse effects, financial constraints, and beliefs about medication, as well as structural barriers.

This stagnation in achieving targets may also be due in part to the increasing proportion of individuals living with diabetes for many years, likely with more severe diabetes that is harder to treat. This issue highlights the importance of diabetes prevention efforts among young people to mitigate long-term complications and improve overall management outcomes.

Despite reductions in the prevalence of CKD and retinopathy, and stable overall cardiovascular disease prevalence, the overall burden of diabetes-related complications remains high. Recent inpatient data highlight a troubling increase in hospitalization rates for end-organ complications, such as heart failure, stroke, and nontraumatic lower extremity amputations, over the past decade, with annual percentage changes of 3.9%, 2.8%, and 5.9%, respectively (109). In addition, hospitalizations for acute complications, such as hyperglycemia and diabetic ketoacidosis, have risen in the last decade. Emergency room use continues to be high, indicating ongoing challenges in managing diabetes (110). These acute care trends could be partially due to less-than-optimal control of risk factors across the population. However, acute care use may also reflect demographic changes, with an aging population living longer with diabetes, diabetes-related complications, and comorbid conditions.

A U.S. population-based study reported that diabetes complications were most prevalent among adults who were of an older age, had a lower income, had achieved a lower level of education, or were classified as having obesity (111). Screening initiatives specifically designed for patients at high risk and those who are underserved could potentially lower the incidence of complications.

The trend in subgroups for risk factor control, preventive screenings, and health behavior measures from 1999 to 2020 presents a multifaceted view of diabetes care in the United States. Age group comparisons indicate that younger adults with diabetes are less likely to achieve risk factor control and adhere to preventive screenings compared to their older counterparts, exposing them to a higher risk of early and severe complications. These issues are further compounded by such barriers as limited healthcare access and psychosocial stressors, particularly depression (112). Depression, in particular, has been linked to worse treatment adherence, poorer self-management practices, and worse clinical outcomes in patients with diabetes (113,114,115). Addressing depression through regular screening and integrated behavioral health interventions is essential to improving diabetes management outcomes and overall quality of care (116).

As shown in the new analyses of national surveillance databases, racial disparities in risk factor control and adherence in preventive measures were persistent. Non-Hispanic Black adults experienced a decline in blood pressure control such that disparities in blood pressure control with other race and ethnicity groups are now larger than ever. In addition, Hispanic adults, including Mexican American adults, face challenges in glycemic and LDL cholesterol management, despite improvements over the years. These groups are less likely to engage in preventive care and health behavior measures, including vaccinations, compared to non-Hispanic White people.

Persistent disparities in diabetes management have been well documented and underscore a healthcare landscape marked by inequalities across race and ethnicity subgroups (117,118,119,120,121,122). From 1999 to 2020, U.S. racial and ethnic minority groups faced greater diabetes prevalence, poorer glycemic control, and higher rates of complications and mortality despite some minor improvement in controlling risk factors (123,124,125). Racial minority populations are less likely to undergo A1C testing or retinopathy screenings in comparison to White adults. These discrepancies in healthcare persist even when there is comparable healthcare access (118). The introduction of newer medications, such as GLP-1 receptor agonists and SGLT2 inhibitors, may exacerbate racial and ethnic disparities in diabetes outcomes, as these medications are less frequently prescribed to Hispanic, non-Hispanic Black, and Asian patients compared to non-Hispanic White patients, largely due to accessibility and affordability challenges (126,127).

To promote consistency and equity of care, evidence-based guidelines should be rigorously applied. Payment systems must be structured to ensure an adequate supply of services and medications to patients from racial and ethnic minority groups and to limit provider incentives that may promote disparities. Furthermore, supporting the use of community health workers and multidisciplinary treatment and preventative care teams can play a crucial role in helping patients navigate the complex healthcare system of the United States (118).

Insurance coverage has long been identified as a key determinant of diabetes care quality, with inadequate coverage linked to higher rates of diabetes and complications (128,129). From 1999 to 2020, adults without health insurance had worsening glycemic control, as well as challenges in obtaining annual screenings and maintaining consistent vaccination rates. In contrast, insured adults experienced modest improvements in multiple domains of risk factor control. For those who are insured, those with Medicaid coverage consistently had lower rates of risk factor control, preventive screening, and health behavior adoption. One study found that this “underinsurance” associated with Medicaid coverage results in high utilization of emergency departments and increased hospitalization rates (110). By focusing efforts on both the uninsured and Medicaid recipients—who frequently fail to achieve risk factor control—strategies can be developed to address health inequities more effectively.

Since the Affordable Care Act (ACA)’s inception in 2010 and widespread implementation in 2013, with its goal to broaden health insurance access for all Americans, there has been an observable shift in the proportion of patients from the uninsured category to Medicaid. This transition may be a contributing factor to the emerging patterns linking insurance status with trends in diabetes health outcomes. Health policies, such as the ACA, can have a significant impact on where and how patients receive diabetes care over the course of their lifetimes. Studying the consequences of past policies can also point to areas of opportunity for ongoing policy reform that might address the unequal public health burden of diabetes.

The needs of population subgroups further reinforce limitations in current quality measures and support the stance taken in the 2024 ADA Standards of Care in Diabetes, which advocates for individualized treatment approaches in diabetes management (130,131). The updated standards also recommend incorporating revisions to care access policies and incorporating value-based payment models that align financial incentives with patient outcomes. Such tailored care recognizes the intricate nature of diabetes and underscores the imperative for a comprehensive, nuanced strategy that caters to the unique needs of varied patient populations, thereby ensuring a more targeted and effective approach in diabetes management.

These findings highlight the need for sustained efforts to address the complex challenges in diabetes care. Although there have been improvements, especially in LDL cholesterol management, preventive screening, and vaccinations, the persistent disparities in risk factor control and care outcomes among younger individuals, racial and ethnic minority groups, and uninsured people remain concerning and warrant further attention.

## Current Quality Measures and Areas for Improvement

Performance measures within healthcare systems and organizations are evolving to better track individualized diabetes care. The core components of diabetes management—glycemic control, blood pressure, and cholesterol—remain essential, yet there is a shift towards more nuanced quality measures that make use of electronic medical records (22,132). Such measures provide targeted responses to specific diagnoses or intermediate outcomes, like adjusting medications in response to cholesterol levels.

With the advent of value-based insurance design (VBID) and Alternative Payment Models (APMs), there is a push for payment reform to align these evolving performance measures with payment incentives, promoting a higher value of care rather than a singular focus on volume of care (133). VBID models focus on reducing out-of-pocket costs for high-value treatments, which could improve medication adherence and patient outcomes. Similarly, APMs encourage healthcare providers to meet certain quality benchmarks, which may include tailored treatments for individuals with diabetes. The integration of VBID and APMs suggests a potential paradigm shift, where measures could be broadened to include patient satisfaction, treatment burden, and the quality-of-life aspects of diabetes management. Operationalizing this expansion of metrics and monitoring needs remains a challenge.

There is a growing recognition that individual patient needs may require different treatment targets, reflecting the heterogeneity within the diabetes population. This shift acknowledges that some individuals can manage diabetes with lifestyle changes alone, while others may require multiple therapies, and one set of treatment targets does not fit all. Older adults may be at risk from stringent A1C control, and patients with multiple coexisting risk factors may benefit from more nuanced treatment strategies (134).

This paradigm shift in diabetes care, which increasingly focuses on the use of medications that have proven benefits beyond glycemic control—such as GLP-1 receptor agonists and SGLT2 inhibitors—has already shown significant improvements in cardiovascular, renal, and weight loss outcomes. However, existing predictive tools like the PREVENT equations, which estimate the risk of CVD, ASCVD, and heart failure, do not yet account for the use of these newer therapies (135,136). Future research will be needed to update these models to include these agents.

As these therapies continue to show broader benefits, they may drive a reevaluation of current quality measures, moving away from traditional target-based metrics (e.g., strict A1C targets) toward a more holistic approach that reflects their broader therapeutic impact. Future quality measures will likely need to incorporate outcomes such as cardiovascular and renal benefits to fully capture the advantages of these newer treatments.

While evolving performance measures help better assess the quality of care provided to individuals with diabetes and improve outcomes, there are potential downsides to expanding the number of quality measures. The cost of systematically collecting representative patient-reported quality-of-care or patient-reported outcome measures data on an ongoing basis is substantial and places additional burdens on already overstretched healthcare resources. Furthermore, as the number of quality-of-care measures increases, providers may struggle to balance these demands with the needs of their patients, potentially detracting from personalized, high-quality care. Therefore, careful consideration must be given when implementing new quality measures to avoid overwhelming healthcare systems and providers.

The criteria used to develop and select performance measures are different from those applied in clinical practice guidelines for making recommendations tailored to individual patients. The Veterans Affairs Quality Enhancement Research Initiative for diabetes management (QUERI-DM) emphasizes a set of criteria to guide quality improvement efforts (137). This initiative focuses on the robustness of measures for care improvement impacting patient outcomes, anticipated risk reduction benefits, clinicians’ reactions to new measures, the need for tailored treatments across different patient groups, and the importance of patient-informed shared decision making to identify patient-preferred, evidence-based care options. Additionally, the expense incurred by organizations in gathering data is important to consider. Frequently, this results in performance metrics that vary from the guidelines suggested in clinical practice (138,139).

The current framework for diabetes quality measurement is predominantly centered on process measures, like completion of recommended screenings, and intermediate outcome measures, such as A1C levels, which are indicators of a patient’s health status and predictors for certain longer-term outcomes, such as end-stage kidney disease and cardiovascular events (22). Despite this focus on process and intermediate outcome measures, substantial enhancements in the overall health of individuals with diabetes have not been achieved (140). A mere fraction of the population meets composite essential management criteria, and since 2015, there has been no substantial decline in severe diabetes-related outcomes (141). The scope of these measures may need broadening to encompass a more holistic view of patient health and healthcare system impact.

While intensifying treatment is often necessary for patients with poor control, there are potential downsides. Incentivizing intensification without considering individual circumstances may lead to overtreatment, increasing clinical risks, such as hypoglycemia or adverse drug effects (142,143). Furthermore, clinicians may hesitate to add new treatments if patients are not adhering to their current medications—a critical factor often overlooked in performance measures. Poor adherence, whether due to side effects or financial barriers, complicates treatment decisions and could inadvertently lead to clinical inertia if unaddressed.

The long-established evidence for treatment targets in diabetes has traditionally emphasized long-term complications, yet for many patients, immediate concerns, such as quality of life, hypoglycemia prevention, and treatment burden, take precedence. Other serious and costly outcomes like infections, hospitalizations, and conditions such as periodontitis and depression are also critical yet are not currently accounted for in diabetes quality indicators. These factors, particularly when leading to repeated hospital readmissions, could be key indicators of quality care.

The prevailing uniform approach to glycemic targets for all patients with diabetes is increasingly being questioned. While performance measures are primarily designed to drive population-level improvements, diverse patient demographics and comorbidities suggest that the one-size-fits-all approach may not be optimal. Moreover, performance measures linked to payment systems might inadvertently focus on patients who are more likely to meet targets, overlooking those with more complex health issues. Most individuals with diabetes have multiple concurrent risk factors and conditions that interact with systemic factors affecting these quality indicators. Also, current measures focusing solely on specific thresholds may overlook significant improvements in patients who fall short of these stringent criteria.

The trend towards personalized goals is growing, with a recognition that tailored care is necessary, particularly for older adults, different subtypes of diabetes, and those with multiple health issues (52,53,144,145,146,147,148). The use of risk prediction models and electronic medical records heralds a future where personalized quality measures could monitor a patient’s changing risk profile for complications and eligibility for treatments.

The 2024 ADA Standards of Care in Diabetes recommendations underscore the need for cohesive, streamlined, modernized quality measures that align with value-based payment models (131). Focusing on a practical set of quality measures applicable to all patients, such as traditional disease-specific metrics, e.g., “ABC,” for quality measure, along with potentially useful measures for specific subgroups, aims to enhance the effectiveness, safety, patient-centeredness, timeliness, efficiency, and equity of diabetes care. The ADA suggests specific quality measures, such as: patient satisfaction and quality-of-life assessments through patient-reported outcomes and satisfaction surveys; health equity measures, addressing social determinants of health and reducing disparities in diabetes care; technology utilization measures, including the use of electronic medical records for tracking and decision support, as well as telehealth services for remote patient monitoring; and care coordination measures, emphasizing team-based care approaches and integrated long-term treatment plans. This integrated approach aims to modernize quality measures in alignment with value-based payment models, encouraging providers to deliver evidence-based care, while focusing on patients with the most to gain due to clinical and socioeconomic factors. This strategy promotes cooperation, reduces administrative burdens, and ultimately strives to evolve the measurement framework to better support comprehensive diabetes care.

The challenges ahead include ensuring equitable care, mitigating health disparities, and preventing the penalization of providers for caring for high-risk patients. Ultimately, the goal is to evolve the measurement framework to better support the effectiveness, safety, patient-centeredness, timeliness, efficiency, and equity of diabetes care.

## Limitations

This study has some limitations. We acknowledge the data used in this study were collected up until 2020, before the widespread use of newer therapies, such as GLP-1 receptor agonists and SGLT2 inhibitors. These emerging therapies have increased in use more recently due to their significant benefits in reducing cardiovascular events, improving renal outcomes, and supporting weight loss. As such, our findings may not fully capture the current trends or the potential impact these medications have had on diabetes management and outcomes.

## Conclusion

The evolving landscape of diabetes care in the United States, as presented herein, highlights both the progress made and the persistent challenges in achieving high-quality care for people with diabetes. Despite advancements in treatment and the implementation of quality metrics, significant gaps remain, particularly in risk factor control and the prevention of diabetes-related complications. The data reveal that while there have been improvements in glycemic, blood pressure, lipid control, and smoking cessation over the past two decades, these gains have plateaued, with some indicators even showing worsening in recent years.

Moreover, disparities in care persist across different race and ethnicity groups, age demographics, and insurance statuses, underscoring the need for targeted and equitable interventions. The trends indicate that younger adults, racial and ethnic minority groups, and those with inadequate insurance coverage are less likely to achieve optimal outcomes, placing them at higher risk for complications.

As diabetes care continues to evolve, there is a growing recognition of the need for personalized treatment approaches to fulfill the diverse needs of the population. The integration of value-based care models and the modernization of quality metrics are steps in the right direction, but ongoing efforts are required to address the complexities of diabetes management. By focusing on individualized care, at a minimum, improving health insurance coverage and access to preventive measures, and addressing social determinants of health, it is possible to enhance the quality of care and reduce the burden of diabetes-related complications in the U.S. population.

## List of Abbreviations

A1C: glycated hemoglobin
ACA: Affordable Care Act
ACC: American College of Cardiology
ACCORD: Action to Control Cardiovascular Risk in Diabetes
ACEi: angiotensin-converting enzyme inhibitor
ADA: American Diabetes Association
AHA: American Heart Association
APM: Alternative Payment Models
ARB: angiotensin II receptor blocker
ASCVD: atherosclerotic cardiovascular disease
BMI: body mass index
CDC: Centers for Disease Control and Prevention
CKD: chronic kidney disease
DCCT: Diabetes Control and Complications Trial
DPP-4: dipeptidyl peptidase-4
eGFR: estimated glomerular filtration rate
GLP-1: glucagon-like peptide-1
HCUP: Healthcare Cost and Utilization Project
IOM: Institute of Medicine
LDL: low-density lipoprotein
MI: myocardial infarction
NCCC: National Clinical Care Commission
NCQA: National Committee for Quality Assurance
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
NIS: National Inpatient Sample
RYGB: Roux-en-Y gastric bypass
SGLT2: sodium-glucose cotransporter-2
UKPDS: United Kingdom Prospective Diabetes Study
VBID: value-based insurance design

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

LDL cholesterol: mg/dL x 0.0259 = mmol/L

## Funding

Dr. Ali is supported by P30DK111024 and 75D30120P0742. Dr. Huang is supported by P50MD017349, K24AG069080, and P30DK092949.

## Acknowledgment

This is an update of: Selvin E, Narayan KMV, Huang ES. Quality of Care in People With Diabetes. Chapter 41 in Diabetes in America, 3rd edition. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 41.1–41.19

## Article History

Received in final form on November 26, 2024.

Originally published on March 6, 2025 and revised on March 17, 2025. This version of the article: (1) corrects race, ethnicity, and insurance status data estimates in Table 1; (2) updates text related to the corrected data in the section “Trends in Characteristics of Adults With Diabetes”; and (3) removes age-standardization labels from Table 11.

## References

1 Centers for Disease Control and Prevention. National Diabetes Statistics Report. Updated May 15, 2024. Accessed January 20, 2025. https://www.cdc.gov/diabetes/php/data-research/?CDC_AAref_Val=https://www.cdc.gov/diabetes/pdfs/data/statistics/national-diabetes-statistics-report.pdf
2 The Commonwealth Fund. U.S. Health Care from a Global Perspective, 2022: Accelerating Spending, Worsening Outcomes. Updated January 31, 2023. Accessed August 6, 2024. https://www.commonwealthfund.org/publications/issue-briefs/2023/jan/us-health-care-global-perspective-2022#:~:text=The%20U.S.%20has%20the%20lowest,19%20vaccination%20trails%20many%20nations
3 Selvin E, Narayan KMV, Huang ES. Quality of Care in People With Diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018; 41.1-41.19:chap 41. https://www.ncbi.nlm.nih.gov/books/NBK568015/
4 Ali MK, Bullard KM, Gregg EW. Achievement of goals in U.S. diabetes care, 1999–2010. N Engl J Med. 2013;369(3):287-288. doi:10.1056/NEJMc1306652
5 Saaddine JB, Cadwell B, Gregg EW, et al. Improvements in diabetes processes of care and intermediate outcomes: United States, 1988–2002. Ann Intern Med. 2006;144(7):465-474. doi:10.7326/0003-4819-144-7-200604040-00005 16585660
6 Fang M, Wang D, Coresh J, Selvin E. Trends in diabetes treatment and control in U.S. adults, 1999–2018. N Engl J Med. 2021;384(23):2219-2228. doi:10.1056/NEJMsa2032271 34107181
7 Stark Casagrande S, Fradkin JE, Saydah SH, Rust KF, Cowie CC. The prevalence of meeting A1C, blood pressure, and LDL goals among people with diabetes, 1988–2010. Diabetes Care. 2013;36(8):2271-2279. doi:10.2337/dc12-2258 23418368
8 Kuznik A, Mardekian J. Trends in utilization of lipid- and blood pressure-lowering agents and goal attainment among the U.S. diabetic population, 1999–2008. Cardiovasc Diabetol. 2011;10(1):31. doi:10.1186/1475-2840-10-31 21496321
9 Saydah SH, Fradkin J, Cowie CC. Poor control of risk factors for vascular disease among adults with previously diagnosed diabetes. JAMA. 2004;291(3):335-342. doi:10.1001/jama.291.3.335 14734596
10 Wang J, Geiss LS, Cheng YJ, et al. Long-term and recent progress in blood pressure levels among U.S. adults with diagnosed diabetes, 1988–2008. Diabetes Care. 2011;34(7):1579-1581. doi:10.2337/dc11-0178 21602427
11 Beaton SJ, Nag SS, Gunter MJ, Gleeson JM, Sajjan SS, Alexander CM. Adequacy of glycemic, lipid, and blood pressure management for patients with diabetes in a managed care setting. Diabetes Care. 2004;27(3):694-698. doi:10.2337/diacare.27.3.694 14988287
12 Smith NL, Chen L, Au DH, McDonell M, Fihn SD. Cardiovascular risk factor control among veterans with diabetes: the Ambulatory Care Quality Improvement Project. Diabetes Care. 2004;27(Suppl 2):B33-B38. doi:10.2337/diacare.27.suppl_2.b33 15113780
13 Selvin E, Parrinello CM, Sacks DB, Coresh J. Trends in prevalence and control of diabetes in the United States, 1988–1994 and 1999–2010. Ann Intern Med. 2014;160(8):517-525. doi:10.7326/M13-2411 24733192
14 Tulloch-Reid M, Williams DE. Quality of diabetes care in the United States between 1988 and 1995. Clinical Diabetes. 2003;21(1):43-45. doi:10.2337/diaclin.21.1.43
15 Thorpe KE, Florence CS, Joski P. Which medical conditions account for the rise in health care spending? Health Aff (Millwood). 2004;Suppl Web Exclusives(Suppl1):W4-437-45. doi:10.1377/hlthaff.w4.437
16 Donabedian A. The quality of care. How can it be assessed? JAMA. 1988;260(12):1743-1748. doi:10.1001/jama.260.12.1743 3045356
17 Derose SF, Petitti DB. Measuring quality of care and performance from a population health care perspective. Annu Rev Public Health. 2003;24(1):363-384. doi:10.1146/annurev.publhealth.24.100901.140847 12471274
18 Institute of Medicine Committee to Design a Strategy for Quality Review Assurance in Medicare. Medicare: A Strategy for Quality Assurance: Volume 1. National Academies Press; 1990. doi:10.17226/1547.
19 Blumenthal D. Part 1: Quality of care—what is it? N Engl J Med. 1996;335(12):891-894. doi:10.1056/NEJM199609193351213 8778612
20 Institute of Medicine Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century, National Academies Press (US); 2001. doi:10.17226/10027.
21 Fleming BB, Greenfield S, Engelgau MM, Pogach LM, Clauser SB, Parrott MA. The Diabetes Quality Improvement Project: moving science into health policy to gain an edge on the diabetes epidemic. Diabetes Care. 2001;24(10):1815-1820. doi:10.2337/diacare.24.10.1815 11574448
22 Jiang DH, O’Connor PJ, Huguet N, Golden SH, McCoy RG. Modernizing diabetes care quality measures. Health Aff (Millwood). 2022;41(7):955-962. doi:10.1377/hlthaff.2022.00233 35759700
23 American Diabetes Association. Economic costs of diabetes in the U.S. in 2017. Diabetes Care. 2018;41(5):917-928. doi:10.2337/dci18-0007 29567642
24 Loeb JM, Buck AS. Framework for selection of performance measurement systems: attributes of conformance. From the Joint Commission on Accreditation of Healthcare Organizations. JAMA. 1996;275(7):508. doi:10.1001/jama.275.7.508 8606459
25 National Committee for Quality Assurance (NCQA). Diabetes Recognition Program. Accessed December 1, 2023. https://www.ncqa.org/programs/health-care-providers-practices/diabetes-recognition-program-drp/
26 National Committee for Quality Assurance (NCQA). Comprehensive Diabetes Care. Accessed September 10, 2023. https://www.ncqa.org/hedis/measures/comprehensive-diabetes-care/
27 MN Community Measurement. MNHealthScores. Accessed December 1, 2023, http://www.mnhealthscores.org.
28 National Clinical Care Commission. Report to Congress on Leveraging Federal Programs to Prevent and Control Diabetes and Its Complications. Accessed January 16, 2025. https://odphp.health.gov/sites/default/files/2022-01/NCCC%20Report%20to%20Congress.pdf
29 Herman WH, Bullock A, Boltri JM, et al. The National Clinical Care Commission Report to Congress: background, methods, and foundational recommendations. Diabetes Care. 2023;46(2):e14-e23. doi:10.2337/dc22-0611 36701594
30 Kontopantelis E, Springate DA, Reeves D, et al. Glucose, blood pressure and cholesterol levels and their relationships to clinical outcomes in type 2 diabetes: a retrospective cohort study. Diabetologia. 2015;58(3):505-518. doi:10.1007/s00125-014-3473-8 25512005
31 Sidorenkov G, Voorham J, de Zeeuw D, Haaijer-Ruskamp FM, Denig P. Do treatment quality indicators predict cardiovascular outcomes in patients with diabetes? PLoS One. 2013;8(10):e78821. doi:10.1371/journal.pone.0078821 24205325
32 National Clinical Care Commission Writing Group, Conlin PR, Greenlee C, et al. The National Clinical Care Commission Report: Improving Federal Programs That Impact Diabetes Prevention and Care. Ann Intern Med. 2022;175(4):594-597. doi:10.7326/M21-4175 35157491
33 O’Connor PJ, Bodkin NL, Fradkin J, et al. Diabetes performance measures: current status and future directions. Diabetes Care. 2011;34(7):1651-1659. doi:10.2337/dc11-0735 21709298
34 Ohkubo Y, Kishikawa H, Araki E, et al. Intensive insulin therapy prevents the progression of diabetic microvascular complications in Japanese patients with non-insulin-dependent diabetes mellitus: a randomized prospective 6-year study. Diabetes Res Clin Pract. 1995;28(2):103-117. doi:10.1016/0168-8227(95)01064-k 7587918
35 Diabetes Control and Complications Trial Research Group, Nathan DM, Genuth S, et al. The effect of intensive treatment of diabetes on the development and progression of long-term complications in insulin-dependent diabetes mellitus. N Engl J Med. 1993;329(14):977-986. doi:10.1056/NEJM199309303291401 8366922
36 Intensive blood-glucose control with sulphonylureas or insulin compared with conventional treatment and risk of complications in patients with type 2 diabetes (UKPDS 33). UK Prospective Diabetes Study (UKPDS) Group. Lancet. 1998;352(9131):837-853. doi:10.1016/S0140-6736(98)07019-6 9742976
37 Effect of intensive blood-glucose control with metformin on complications in overweight patients with type 2 diabetes (UKPDS 34). UK Prospective Diabetes Study (UKPDS) Group. Lancet. 1998;352(9131):854-865. doi:10.1016/S0140-6736(98)07037-8 9742977
38 Beck RW, Connor CG, Mullen DM, Wesley DM, Bergenstal RM. The fallacy of average: how using HbA(1c) alone to assess glycemic control can be misleading. Diabetes Care. 2017;40(8):994-999. doi:10.2337/dc17-0636 28733374
39 Kushner PR, Kruger DF. The changing landscape of glycemic targets: focus on continuous glucose monitoring. Clin Diabetes. 2020;38(4):348-356. doi:10.2337/cd19-0093 33132504
40 Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Research Group, Lachin JM, Genuth S, Cleary P, Davis MD, Nathan DM. Retinopathy and nephropathy in patients with type 1 diabetes four years after a trial of intensive therapy. N Engl J Med. 2000;342(6):381-389. doi:10.1056/NEJM200002103420603 10666428
41 Nathan DM, Cleary PA, Backlund JY, et al. Intensive diabetes treatment and cardiovascular disease in patients with type 1 diabetes. N Engl J Med. 2005;353(25):2643-2653. doi:10.1056/NEJMoa052187 16371630
42 Martin CL, Albers J, Herman WH, et al. Neuropathy among the Diabetes Control and Complications Trial cohort 8 years after trial completion. Diabetes Care. 2006;29(2):340-344. doi:10.2337/diacare.29.02.06.dc05-1549 16443884
43 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA. 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med. 2008;359(15):1577-1589. doi:10.1056/NEJMoa0806470 18784090
44 Adler AI, Coleman RL, Leal J, Whiteley WN, Clarke P, Holman RR. Post-trial monitoring of a randomised controlled trial of intensive glycaemic control in type 2 diabetes extended from 10 years to 24 years (UKPDS 91). Lancet. 2024;404(10448):145-155. doi:10.1016/S0140-6736(24)00537-3 38772405
45 Selvin E, Steffes MW, Zhu H, et al. Glycated hemoglobin, diabetes, and cardiovascular risk in nondiabetic adults. N Engl J Med. 2010;362(9):800-811. doi:10.1056/NEJMoa0908359 20200384
46 ADVANCE Collaborative Group, Patel A, MacMahon S, et al. Intensive blood glucose control and vascular outcomes in patients with type 2 diabetes. N Engl J Med. 2008;358(24):2560-2572. doi:10.1056/NEJMoa0802987 18539916
47 Skyler JS, Bergenstal R, Bonow RO, et al. Intensive Glycemic Control and the Prevention of Cardiovascular Events: Implications of the ACCORD, ADVANCE, and VA Diabetes Trials: a position statement of the American Diabetes Association and a scientific statement of the American College of Cardiology Foundation and the American Heart Association. Circulation. 2009;119(2):351-357. doi:10.1161/CIRCULATIONAHA.108.191305 19095622
48 Duckworth W, Abraira C, Moritz T, et al. Glucose control and vascular complications in veterans with type 2 diabetes. N Engl J Med. 2009;360(2):129-139. doi:10.1056/NEJMoa0808431 19092145
49 ACCORD Study Group, Cushman WC, Evans GW, et al. Effects of intensive blood-pressure control in type 2 diabetes mellitus. N Engl J Med. 2010;362(17):1575-1585. doi:10.1056/NEJMoa1001286 20228401
50 Action to Control Cardiovascular Risk in Diabetes Study Group, Gerstein HC, Miller ME, et al. Effects of intensive glucose lowering in type 2 diabetes. N Engl J Med. 2008;358(24):2545-2559. doi:10.1056/NEJMoa0802743 18539917
51 American Diabetes Association. Standards of Medical Care in Diabetes—2012. Diabetes Care. 2012;35(Supplement_1):S11-S63. doi:10.2337/dc12-S011 22187469
52 Inzucchi SE, Bergenstal RM, Buse JB, et al. Management of Hyperglycemia in Type 2 Diabetes: A Patient-Centered Approach: position statement of the American Diabetes Association (ADA) and the European Association for the Study of Diabetes (EASD). Diabetes Care. 2012;35(6):1364-1379. doi:10.2337/dc12-0413 22517736
53 ElSayed NA, Aleppo G, Aroda VR, et al. 10. Cardiovascular Disease and Risk Management: Standards of Care in Diabetes-2023. Diabetes Care. 2023;46(Suppl 1):S158-S190. doi:10.2337/dc23-S010 36507632
54 Whelton PK, Carey RM, Aronow WS, et al. 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the Prevention, Detection, Evaluation, and Management of High Blood Pressure in Adults: a report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. J Am Coll Cardiol. 2018;71(19):e127-e248. doi:10.1016/j.jacc.2017.11.006 29146535
55 de Boer IH, Bakris G, Cannon CP. Individualizing blood pressure targets for people with diabetes and hypertension: comparing the ADA and the ACC/AHA recommendations. JAMA. 2018;319(13):1319-1320. doi:10.1001/jama.2018.0642 29543954
56 Patel A, ADVANCE Collaborative Group, MacMahon S, et al. Effects of a fixed combination of perindopril and indapamide on macrovascular and microvascular outcomes in patients with type 2 diabetes mellitus (the ADVANCE trial): a randomised controlled trial. Lancet. 2007;370(9590):829-840. doi:10.1016/S0140-6736(07)61303-8 17765963
57 Sink KM, Evans GW, Shorr RI, et al. Syncope, hypotension, and falls in the treatment of hypertension: results from the randomized clinical systolic blood pressure intervention trial. J Am Geriatr Soc. 2018;66(4):679-686. doi:10.1111/jgs.15236 29601076
58 Bangalore S, Kumar S, Lobach I, Messerli FH. Blood pressure targets in subjects with type 2 diabetes mellitus/impaired fasting glucose: observations from traditional and bayesian random-effects meta-analyses of randomized trials. Circulation. 2011;123(24):2799-2810. doi:10.1161/CIRCULATIONAHA.110.016337 21632497
59 Basu S, Sussman JB, Rigdon J, Steimle L, Denton BT, Hayward RA. Benefit and harm of intensive blood pressure treatment: derivation and validation of risk models using data from the SPRINT and ACCORD trials. PLoS Med. 2017;14(10):e1002410. doi:10.1371/journal.pmed.1002410 29040268
60 Phillips RA, Xu J, Peterson LE, Arnold RM, Diamond JA, Schussheim AE. Impact of cardiovascular risk on the relative benefit and harm of intensive treatment of hypertension. J Am Coll Cardiol. 2018;71(15):1601-1610. doi:10.1016/j.jacc.2018.01.074 29525494
61 Hansson L, Zanchetti A, Carruthers SG, et al. Effects of intensive blood-pressure lowering and low-dose aspirin in patients with hypertension: principal results of the Hypertension Optimal Treatment (HOT) randomised trial. HOT Study Group. Lancet. 1998;351(9118):1755-1762. doi:10.1016/s0140-6736(98)04311-6 9635947
62 Brunström M, Carlberg B. Effect of antihypertensive treatment at different blood pressure levels in patients with diabetes mellitus: systematic review and meta-analyses. BMJ. 2016;352:i717. doi:10.136/bmj.i717 26920333
63 Ettehad D, Emdin CA, Kiran A, et al. Blood pressure lowering for prevention of cardiovascular disease and death: a systematic review and meta-analysis. Lancet. 2016;387(10022):957-967. doi:10.1016/S0140-6736(15)01225-8 26724178
64 Emdin CA, Rahimi K, Neal B, Callender T, Perkovic V, Patel A. Blood pressure lowering in type 2 diabetes: a systematic review and meta-analysis. JAMA. 2015;313(6):603-615. doi:10.1001/jama.2014.18574 25668264
65 SPRINT Research Group, Wright JT, Jr., Williamson JD, et al. A randomized trial of intensive versus standard blood-pressure control. N Engl J Med. 2015;373(22):2103-2116. doi:10.1056/NEJMoa1511939 26551272
66 American Diabetes Association Professional Practice Committee. 10. Cardiovascular Disease and Risk Management: Standards of Care in Diabetes—2024. Diabetes Care. 2023;47(Supplement_1):S179-S218. doi:10.2337/dc24-S010
67 Wright JT, Jr., Whelton PK, Reboussin DM. A randomized trial of intensive versus standard blood-pressure control. N Engl J Med. 2016;374(23):2294. doi:10.1056/NEJMc1602668 27276569
68 American Diabetes Association Professional Practice Committee. 10. Cardiovascular Disease and Risk Management: Standards of Care in Diabetes-2024. Diabetes Care. 2024;47(Suppl 1):S179-S218. doi:10.2337/dc24-S010 38078592
69 American Diabetes Association. Standards of Care in Diabetes-2023 Abridged for Primary Care Providers. Clin Diabetes. 2022;41(1):4-31. doi:10.2337/cd23-as01 36714254
70 Cholesterol Treatment Trialists (CTT) Collaborators, Mihaylova B, Emberson J, et al. The effects of lowering LDL cholesterol with statin therapy in people at low risk of vascular disease: meta-analysis of individual data from 27 randomised trials. Lancet. 2012;380(9841):581-590. doi:10.1016/S0140-6736(12)60367-5 22607822
71 Baigent C, Keech A, Kearney P, et al. Efficacy and safety of cholesterol-lowering treatment: prospective meta-analysis of data from 90,056 participants in 14 randomised trials of statins. Lancet. 2005;366:1267-1278. doi:10.1016/S0140-6736(05)67394-1 16214597
72 Knopp RH, d’Emden M, Smilde JG, Pocock SJ. Efficacy and safety of atorvastatin in the prevention of cardiovascular end points in subjects with type 2 diabetes: the Atorvastatin Study for Prevention of Coronary Heart Disease Endpoints in Non-Insulin-Dependent Diabetes Mellitus (ASPEN). Diabetes Care. 2006;29(7):1478-1485. doi:10.2337/dc05-2415 16801565
73 Colhoun HM, Betteridge DJ, Durrington PN, et al. Primary prevention of cardiovascular disease with atorvastatin in type 2 diabetes in the Collaborative Atorvastatin Diabetes Study (CARDS): multicentre randomised placebo-controlled trial. Lancet. 2004;364(9435):685-696. doi:10.1016/S0140-6736(04)16895-5 15325833
74 Writing Committee, Lloyd-Jones DM, Morris PB, et al. 2022 ACC Expert Consensus Decision Pathway on the Role of Nonstatin Therapies for LDL-Cholesterol Lowering in the Management of Atherosclerotic Cardiovascular Disease Risk: a report of the American College of Cardiology Solution Set Oversight Committee. J Am Coll Cardiol. 2022;80(14):1366-1418. doi:10.1016/j.jacc.2022.07.006 36031461
75 Grundy SM, Stone NJ, Bailey AL, et al. 2018 AHA/ACC/AACVPR/AAPA/ABC/ACPM/ADA/AGS/APhA/ASPC/NLA/PCNA Guideline on the Management of Blood Cholesterol: a report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. J Am Coll Cardiol. 2019;73(24):e285-e350. doi:10.1016/j.jacc.2018.11.003 30423393
76 Gæde P, Vedel P, Larsen N, Jensen GV, Parving HH, Pedersen O. Multifactorial intervention and cardiovascular disease in patients with type 2 diabetes. N Engl J Med. 2003;348(5):383-393. doi:10.1056/NEJMoa021778 12556541
77 Gæde P, Lund-Andersen H, Parving HH, Pedersen O. Effect of a multifactorial intervention on mortality in type 2 diabetes. N Engl J Med. 2008;358(6):580-591. doi:10.1056/NEJMoa0706245 18256393
78 ASCEND Study Collaborative Group, Bowman L, Mafham M, et al. Effects of aspirin for primary prevention in persons with diabetes mellitus. N Engl J Med. 2018;379(16):1529-1539. doi:10.1056/NEJMoa1804988 30146931
79 McGuire DK, Shih WJ, Cosentino F, et al. Association of SGLT2 inhibitors with cardiovascular and kidney outcomes in patients with type 2 diabetes: a meta-analysis. JAMA Cardiol. 2021;6(2):148-158. doi:10.1001/jamacardio.2020.4511 33031522
80 Zinman B, Wanner C, Lachin JM, et al. Empagliflozin, cardiovascular outcomes, and mortality in type 2 diabetes. N Engl J Med. 2015;373(22):2117-2128. doi:10.1056/NEJMoa1504720 26378978
81 Neal B, Perkovic V, Mahaffey KW, et al. Canagliflozin and cardiovascular and renal events in type 2 diabetes. N Engl J Med. 2017;377(7):644-657. doi:10.1056/NEJMoa1611925 28605608
82 Bakris GL. Major advancements in slowing diabetic kidney disease progression: focus on SGLT2 inhibitors. Am J Kidney Dis. 2019;74(5):573-575. doi:10.1053/j.ajkd.2019.05.009 31262591
83 Perkovic V, Jardine MJ, Neal B, et al. Canagliflozin and renal outcomes in type 2 diabetes and nephropathy. N Engl J Med. 2019;380(24):2295-2306. doi:10.1056/NEJMoa1811744 30990260
84 Heerspink HJL, Stefánsson BV, Correa-Rotter R, et al. Dapagliflozin in patients with chronic kidney disease. N Engl J Med. 2020;383(15):1436-1446. doi:10.1056/NEJMoa2024816 32970396
85 McMurray JJV, Solomon SD, Inzucchi SE, et al. Dapagliflozin in patients with heart failure and reduced ejection fraction. N Engl J Med. 2019;381(21):1995-2008. doi:10.1056/NEJMoa1911303 31535829
86 Garvey WT, Frias JP, Jastreboff AM, et al. Tirzepatide once weekly for the treatment of obesity in people with type 2 diabetes (SURMOUNT-2): a double-blind, randomised, multicentre, placebo-controlled, phase 3 trial. Lancet. 2023;402(10402):613-626. doi:10.1016/S0140-6736(23)01200-X 37385275
87 Davies M, Færch L, Jeppesen OK, et al. Semaglutide 2.4 mg once a week in adults with overweight or obesity, and type 2 diabetes (STEP 2): a randomised, double-blind, double-dummy, placebo-controlled, phase 3 trial. Lancet. 2021;397(10278):971-984. doi:10.1016/S0140-6736(21)00213-0 33667417
88 Davies MJ, Bergenstal R, Bode B, et al. Efficacy of liraglutide for weight loss among patients with type 2 diabetes: the SCALE diabetes randomized clinical trial. JAMA. 2015;314(7):687-699. doi:10.1001/jama.2015.9676 26284720
89 Marso SP, Daniels GH, Brown-Frandsen K, et al. Liraglutide and cardiovascular outcomes in type 2 diabetes. N Engl J Med. 2016;375(4):311-322. doi:10.1056/NEJMoa1603827 27295427
90 Zelniker TA, Wiviott SD, Raz I, et al. Comparison of the effects of glucagon-like peptide receptor agonists and sodium-glucose cotransporter 2 inhibitors for prevention of major adverse cardiovascular and renal outcomes in type 2 diabetes mellitus: systematic review and meta-analysis of cardiovascular outcomes trials. Circulation. 2019;139(17):2022-2031. doi:10.1161/CIRCULATIONAHA.118.038868 30786725
91 Mann JFE, Hansen T, Idorn T, et al. Effects of once-weekly subcutaneous semaglutide on kidney function and safety in patients with type 2 diabetes: a post-hoc analysis of the SUSTAIN 1-7 randomised controlled trials. Lancet Diabetes Endocrinol. 2020;8(11):880-893. doi:10.1016/S2213-8587(20)30313-2 32971040
92 Sattar N, Lee MMY, Kristensen SL, et al. Cardiovascular, mortality, and kidney outcomes with GLP-1 receptor agonists in patients with type 2 diabetes: a systematic review and meta-analysis of randomised trials. Lancet Diabetes Endocrinol. 2021;9(10):653-662. doi:10.1016/S2213-8587(21)00203-5 34425083
93 Qaseem A, Obley AJ, Shamliyan T, et al. Newer Pharmacologic Treatments in Adults With Type 2 Diabetes: a clinical guideline from the American College of Physicians. Ann Intern Med. 2024;177(5):658-666. doi:10.7326/M23-2788 38639546
94 Drake T, Landsteiner A, Langsetmo L, et al. Newer pharmacologic treatments in adults with type 2 diabetes: a systematic review and network meta-analysis for the American College of Physicians. Ann Intern Med. 2024;177(5):618-632. doi:10.7326/M23-1490 38639549
95 Xie Y, Bowe B, Xian H, Loux T, McGill JB, Al-Aly Z. Comparative effectiveness of SGLT2 inhibitors, GLP-1 receptor agonists, DPP-4 inhibitors, and sulfonylureas on risk of major adverse cardiovascular events: emulation of a randomised target trial using electronic health records. Lancet Diabetes Endocrinol. 2023;11(9):644-656. doi:10.1016/S2213-8587(23)00171-7 37499675
96 Khera R, Aminorroaya A, Dhingra LS, et al. Comparative effectiveness of second-line antihyperglycemic agents for cardiovascular outcomes: a multinational, federated analysis of LEGEND-T2DM. J Am Coll Cardiol. 2024;84(10):904-917. doi:10.1016/j.jacc.2024.05.069 39197980
97 McCoy RG, Van Houten HK, Karaca-Mandic P, Ross JS, Montori VM, Shah ND. Second-line therapy for type 2 diabetes management: the treatment/benefit paradox of cardiovascular and kidney comorbidities. Diabetes Care. 2021;44(10):2302-2311. doi:10.2337/dc20-2977 34348996
98 Rosenstock J, Wysham C, Frías JP, et al. Efficacy and safety of a novel dual GIP and GLP-1 receptor agonist tirzepatide in patients with type 2 diabetes (SURPASS-1): a double-blind, randomised, phase 3 trial. Lancet. 2021;398(10295):143-155. doi:10.1016/S0140-6736(21)01324-6 34186022
99 Ala M, Mohammad Jafari R, Dehpour AR, Poursalehian M. Tirzepatide outcompetes long-acting insulin in managing type 2 diabetes: a meta-analysis of three phase 3 randomized controlled trials. Int J Obes (Lond). 2024:1684-1695. doi:10.1038/s41366-024-01621-4 39210008
100 Bakris GL, Agarwal R, Anker SD, et al. Effect of finerenone on chronic kidney disease outcomes in type 2 diabetes. N Engl J Med. 2020;383(23):2219-2229. doi:10.1056/NEJMoa2025845 33264825
101 American Diabetes Association Professional Practice Committee. 8. Obesity and Weight Management for the Prevention and Treatment of Type 2 Diabetes: Standards of Care in Diabetes–2024. Diabetes Care. 2024;47(Supplement_1):S145-S157. doi:10.2337/dc24-S008 38078578
102 Schauer PR, Bhatt DL, Kirwan JP, et al. Bariatric surgery versus intensive medical therapy for diabetes—5-year outcomes. N Engl J Med. 2017;376(7):641-651. doi:10.1056/NEJMoa1600869 28199805
103 Kirwan JP, Courcoulas AP, Cummings DE, et al. Diabetes remission in the Alliance of Randomized Trials of Medicine Versus Metabolic Surgery in Type 2 Diabetes (ARMMS-T2D). Diabetes Care. 2022;45(7):1574-1583. doi:10.2337/dc21-2441 35320365
104 Mingrone G, Panunzi S, De Gaetano A, et al. Metabolic surgery versus conventional medical therapy in patients with type 2 diabetes: 10-year follow-up of an open-label, single-centre, randomised controlled trial. Lancet. 2021;397(10271):293-304. doi:10.1016/S0140-6736(20)32649-0 33485454
105 Casagrande SS, Park J, Herman WH, McKeever Bullard K. Health Insurance and Diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597725/
106 Chehal PK, Uppal TS, Turbow S, et al. Continuity of medication use by US adults with diabetes, 2005–2019. JAMA Netw Open. 2023;6(1):e2253562. doi:10.1001/jamanetworkopen.2022.53562 36716032
107 Weiss T, Carr RD, Pal S, et al. Real-world adherence and discontinuation of glucagon-like peptide-1 receptor agonists therapy in type 2 diabetes mellitus patients in the United States. Patient Prefer Adherence. 2020;14:2337-2345. doi:10.2147/PPA.S277676 33273810
108 Ofori-Asenso R, Sahle BW, Chin KL, et al. Poor adherence and persistence to sodium glucose co-transporter 2 inhibitors in real-world settings: evidence from a systematic review and meta-analysis. Diabetes Metab Res Rev. 2021;37(1):e3350. doi:10.1002/dmrr.3350 32447808
109 Saelee R, Bullard KM, Hora IA, et al. Trends and inequalities in diabetes-related complications among U.S. adults, 2000–2020. Diabetes Care. 2025;48(1):18-28. doi:10.2337/dci24-0022 38905540
110 Uppal TS, Chehal PK, Fernandes G, et al. Trends and variations in emergency department use associated with diabetes in the US by sociodemographic factors, 2008–2017. JAMA Netw Open. 2022;5(5):e2213867. doi:10.1001/jamanetworkopen.2022.13867 35612855
111 Fang M, Selvin E. Thirty-year trends in complications in U.S. adults with newly diagnosed type 2 diabetes. Diabetes Care. 2021;44(3):699-706. doi:10.2337/dc20-2304 33419932
112 McCoy RG, Kidney RSM, Holznagel D, Peters T, Madzura V. Challenges for younger adults with diabetes. Minn Med. 2019;102(2):34-36. 31889734
113 Derese A, Gebreegzhiabhere Y, Medhin G, Sirgu S, Hanlon C. Impact of depression on self-efficacy, illness perceptions and self-management among people with type 2 diabetes: a systematic review of longitudinal studies. PLoS One. 2024;19(5):e0302635. doi:10.1371/journal.pone.0302635 38709771
114 Mut-Vitcu G, Timar B, Timar R, Oancea C, Citu IC. Depression influences the quality of diabetes-related self-management activities in elderly patients with type 2 diabetes: a cross-sectional study. Clin Interv Aging. 2016;11:471-479. doi:10.2147/CIA.S104083 27217731
115 Gonzalez JS, Peyrot M, McCarl LA, et al. Depression and diabetes treatment nonadherence: a meta-analysis. Diabetes Care. 2008;31(12):2398-2403. doi:10.2337/dc08-1341 19033420
116 McMorrow R, Hunter B, Hendrieckx C, et al. Effect of routinely assessing and addressing depression and diabetes distress on clinical outcomes among adults with type 2 diabetes: a systematic review. BMJ Open. 2022;12(5):e054650. doi:10.1136/bmjopen-2021-054650
117 Virnig BA, Lurie N, Huang Z, Musgrave D, McBean AM, Dowd B. Racial variation in quality of care among Medicare+Choice enrollees. Health Aff (Millwood). 2002;21(6):224-230. doi:10.1377/hlthaff.21.6.224
118 Nelson A. Unequal treatment: confronting racial and ethnic disparities in health care. J Natl Med Assoc. 2002;94(8):666-668. 12152921
119 Simonetti JA, Fine MJ, Chen YF, Simak D, Hess R. Racial comparisons of diabetes care and intermediate outcomes in a patient-centered medical home. Diabetes Care. 2014;37(4):993-1001. doi:10.2337/dc13-1332 24255103
120 Trivedi AN, Zaslavsky AM, Schneider EC, Ayanian JZ. Trends in the quality of care and racial disparities in Medicare managed care. N Engl J Med. 2005;353(7):692-700. doi:10.1056/NEJMsa051207 16107622
121 Mensah P, Valdez K, Gyawali A, Snell-Bergeon J. Social and structural determinants of cardiovascular complications of diabetes. Curr Diab Rep. 2024;24(7):147-157. doi:10.1007/s11892-024-01541-7 38696042
122 Kahkoska AR, Shay CM, Crandell J, et al. Association of race and ethnicity with glycemic control and hemoglobin A(1c) levels in youth with type 1 diabetes. JAMA Netw Open. 2018;1(5):e181851. doi:10.1001/jamanetworkopen.2018.1851 30370425
123 Haw JS, Shah M, Turbow S, Egeolu M, Umpierrez G. Diabetes complications in racial and ethnic minority populations in the USA. Curr Diab Rep. 2021;21(1):2. doi:10.1007/s11892-020-01369-x 33420878
124 Canedo JR, Miller ST, Schlundt D, Fadden MK, Sanderson M. Racial/ethnic disparities in diabetes quality of care: the role of healthcare access and socioeconomic status. J Racial Ethn Health Disparities. 2018;5(1):7-14. doi:10.1007/s40615-016-0335-8 28078660
125 Trivedi AN, Grebla RC, Wright SM, Washington DL. Despite improved quality of care in the Veterans Affairs health system, racial disparity persists for important clinical outcomes. Health Aff (Millwood). 2011;30(4):707-715. doi:10.1377/hlthaff.2011.0074 21471492
126 Vasti EC, Basina M, Calma J, Maron DJ, Rodriguez F, Sandhu AT. Disparities in adoption of new diabetic therapies with cardiovascular benefits. Diabetes Res Clin Pract. 2023;196:110233. doi:10.1016/j.diabres.2022.110233 36581144
127 Bepo L, Nguyen OK, Makam AN. Disparities in use of novel diabetes medications by insurance: a nationally representative cohort study. J Gen Intern Med. 2024;39(15):2987-2994. doi:10.1007/s11606-024-08961-x 39085578
128 Zhang JX, Huang ES, Drum ML, et al. Insurance status and quality of diabetes care in community health centers. Am J Public Health. 2009;99(4):742-747. doi:10.2105/AJPH.2007.125534 18799773
129 Doucette ED, Salas J, Scherrer JF. Insurance coverage and diabetes quality indicators among patients in NHANES. Am J Manag Care. 2016;22(7):484-490. 27442204
130 ElSayed NA, Aleppo G, Aroda VR, et al. Summary of Revisions: Standards of Care in Diabetes-2023. Diabetes Care. 2023;46(Suppl 1):S5-S9. doi:10.2337/dc23-Srev 36507641
131 American Diabetes Association Professional Practice Committee. 1. Improving Care and Promoting Health in Populations: Standards of Care in Diabetes-2024. Diabetes Care. 2024;47(Suppl 1):S11-S19. doi:10.2337/dc24-S001 38078573
132 Kerr EA, Krein SL, Vijan S, Hofer TP, Hayward RA. Avoiding pitfalls in chronic disease quality measurement: a case for the next generation of technical quality measures. Am J Manag Care. 2001;7(11):1033-1043. 11725807
133 Wang S, Weyer G, Duru OK, Gabbay RA, Huang ES. Can alternative payment models and value-based insurance design alter the course of diabetes in the United States? Health Aff (Millwood). 2022;41(7):980-984. doi:10.1377/hlthaff.2022.00235 35759703
134 Selby JV, Uratsu CS, Fireman B, et al. Treatment intensification and risk factor control: toward more clinically relevant quality measures. Med Care. 2009;47(4):395-402. doi:10.1097/mlr.0b013e31818d775c 19330888
135 Khan SS, Coresh J, Pencina MJ, et al. Novel Prediction Equations for Absolute Risk Assessment of Total Cardiovascular Disease Incorporating Cardiovascular-Kidney-Metabolic Health: a scientific statement from the American Heart Association. Circulation. 2023;148(24):1982-2004. doi:10.1161/CIR.0000000000001191 37947094
136 Khan SS, Matsushita K, Sang Y, et al. Development and validation of the American Heart Association’s PREVENT equations. Circulation. 2024;149(6):430-449. doi:10.1161/CIRCULATIONAHA.123.067626 37947085
137 Hayward RA, Hofer TP, Kerr EA, Krein SL. Quality improvement initiatives: issues in moving from diabetes guidelines to policy. Diabetes Care. 2004;27(Suppl 2):B54-B60. doi:10.2337/diacare.27.suppl_2.b54 15113784
138 Anderson JL, Heidenreich PA, Barnett PG, et al. ACC/AHA statement on cost/value methodology in clinical practice guidelines and performance measures: a report of the American College of Cardiology/American Heart Association Task Force on Performance Measures and Task Force on Practice Guidelines. Circulation. 2014;129(22):2329-2345. doi:10.1161/CIR.0000000000000042 24677315
139 O’Kane ME, Pawlson G. Diabetes quality measures. JAMA. 2011;305(19):1966-1967. doi:10.1001/jama.2011.642
140 Takahashi PY, St Sauver JL, Finney Rutten LJ, et al. Health outcomes in diabetics measured with Minnesota Community Measurement quality metrics. Diabetes Metab Syndr Obes. 2015;8:1-8. doi:10.2147/DMSO.S71726 25565873
141 Centers for Disease Control and Prevention. United States Diabetes Surveillance System: Surveillance. Accessed March 7, 2024, https://gis.cdc.gov/grasp/diabetes/diabetesatlas-surveillance.html
142 McCoy RG, Lipska KJ, Yao X, Ross JS, Montori VM, Shah ND. Intensive treatment and severe hypoglycemia among adults with type 2 diabetes. JAMA Intern Med. 2016;176(7):969-978. doi:10.1001/jamainternmed.2016.2275 27273792
143 Tseng CL, Soroka O, Maney M, Aron DC, Pogach LM. Assessing potential glycemic overtreatment in persons at hypoglycemic risk. JAMA Intern Med. 2014;174(2):259-268. doi:10.1001/jamainternmed.2013.12963 24322626
144 Konnyu KJ, Yogasingam S, Lepine J, et al. Quality improvement strategies for diabetes care: effects on outcomes for adults living with diabetes. Cochrane Database Syst Rev. 2023;5(5):CD014513. doi:10.1002/14651858.CD014513 37254718
145 ElSayed NA, Aleppo G, Aroda VR, et al. 13. Older Adults: Standards of Care in Diabetes-2023. Diabetes Care. 2023;46(Suppl 1):S216-S229. doi:10.2337/dc23-S013 36507638
146 ElSayed NA, Aleppo G, Aroda VR, et al. 6. Glycemic Targets: Standards of Care in Diabetes-2023. Diabetes Care. 2023;46(Suppl 1):S97-S110. doi:10.2337/dc23-S006 36507646
147 ElSayed NA, Aleppo G, Aroda VR, et al. 4. Comprehensive Medical Evaluation and Assessment of Comorbidities: Standards of Care in Diabetes-2023. Diabetes Care. 2023;46(Suppl 1):S49-S67. doi:10.2337/dc23-S004 36507651
148 Chung WK, Erion K, Florez JC, et al. Precision Medicine in Diabetes: a Consensus Report From the American Diabetes Association (ADA) and the European Association for the Study of Diabetes (EASD). Diabetes Care. 2020;43(7):1617-1635. doi:10.2337/dci20-0022 32561617

FIGURE 1.

Age-Standardized Trends in Risk Factor Control Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020.

Diabetes and smoking statuses are self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20-44, 45-64, and ≥65 years. Error bars represent 95% confidence intervals. Conversion formulas for A1C and LDL cholesterol values are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein.

* A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graphs showing stable glycemic control, an increase in blood pressure and cholesterol control, and an increase in control for all three risk factors among adults with diabetes between 1999 and 2020.

FIGURE 2.

Distributions of Medication Use Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020.

All data are self-reported. Estimates are age-sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Error bars represent 95% confidence intervals.

*Any glucose-lowering medications include insulin, metformin, sulfonylureas, dipeptidyl peptidase-4 (DPP-4) inhibitors, glucagon-like peptide-1 (GLP-1) receptor agonists, sodium-glucose cotransporter-2 (SGLT2) inhibitors, and thiazolidinediones.

† Any blood pressure-lowering medications include angiotensin-converting enzyme (ACE) inhibitors, angiotensin II receptor blockers (ARBs), calcium channel blockers (CCBs), beta blockers, and other medications.

‡ Any lipid-lowering medications include statins and others.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Bar graph showing an increase in use of glucose lowering, blood pressure lowering, and lipid lowering medications among adults with diabetes between 1999 and 2020.

FIGURE 3.

Age-Standardized Trends in the Prevalence of Complications Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020.

Diabetes status, cardiovascular disease, and retinopathy are self-reported. Estimates are age-sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Any cardiovascular disease includes coronary heart disease, congestive heart failure, and stroke.

† Any chronic kidney disease includes estimated glomerular filtration rate (eGRF) <60 mL/min/1.73 m^2^ or urine albumin to creatinine ratio (ACR) ≥300 mg/mmol.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graph showing that cardiovascular disease and chronic kidney disease complications were stable between 1999 and 2020 among adults with diabetes while retinopathy decreased.

FIGURE 4.

Trends in the Incidence of Diabetes-Related Hospital Discharges Among Adults Age ≥20 Years With Diabetes, U.S., 2000–2020.

Diabetes is defined by ICD-9 code (250, 357.2, 362.0, 366.41, 648.0, and 775) or ICD-10 code (E10 for type 1 diabetes or E11 for type 2 diabetes). Types of hospital discharges are based on ICD-9 and ICD-10 codes, any diagnosis code. Estimates are age-sex-race/ethnicity standardized to the HCUP 2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. ICD-9/10, International Classification of Diseases, 9th/10th Revision.

* Lower extremity amputation includes amputations at the hip, above the knee, below the knee, and at the foot level.

† Hypoglycemia is defined as diagnoses related to hypoglycemic conditions, including diabetes-related or drug-induced hypoglycemia.

SOURCE: Healthcare Cost and Utilization Project (HCUP)-National Inpatient Surveys 2000–2020

Line graph showing that hospital discharges for ketoacidosis and hypoglycemia nearly doubled between 2000 and 2020 among adults with diabetes while hospital discharges for diabetes related coma decreased.

FIGURE 5.

Trends in Risk Factor Control Among Adults Age ≥20 Years With Diagnosed Diabetes, by Age, U.S., 1999–March 2020.

Diabetes and smoking statuses are self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol values are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein.

* A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not a current smoker

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graphs showing that control of A 1 C, blood pressure, L D L cholesterol, and being a non-smoker among adults with diagnosed diabetes significantly improved between 1999 and 2020 for adults equal to or greater than 45 years but decreased slightly for adults age 20 to 45 years.

FIGURE 6.

Age-Standardized Trends in Risk Factor Control Among Adults Age ≥20 Years With Diagnosed Diabetes, by Race and Ethnicity, U.S., 1999–March 2020.

Diabetes and smoking statuses are self-reported. No data are available for non-Hispanic Asians prior to 2011. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol values are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein.

* A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graphs showing that control of A 1 C, blood pressure, L D L cholesterol, and being a non-smoker among adults with diagnosed diabetes significantly improved for all race and ethnic groups between 1999 and 2020 with non-Hispanic Asian having the highest prevalence of risk factor control.

FIGURE 7.

Age-Standardized Trends in Risk Factor Control Among Adults Age ≥20 Years With Diagnosed Diabetes, by Insurance Status, U.S., 1999–March 2020.

Diabetes, smoking, and insurance statuses are self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol values are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein.

* A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ For the “No insurance” group in 1999–2004 and 2017–2020, the estimates for composite measure achievement (Panel E) are too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graphs showing that control of A 1 C, blood pressure, L D L cholesterol, and being a non-smoker among adults with diagnosed diabetes significantly increased for those with health insurance between 1999 and 2020 and control of these risk factors was lower for those without insurance.

FIGURE 8.

Age-Standardized Trends in Risk Factor Control Among Adults Age ≥20 Years With Diagnosed Diabetes, by Insurance Type, U.S., 1999–March 2020.

Diabetes, smoking, and insurance statuses are self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol values are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein.

* A1C <8.0%, blood pressure <140/90mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ The estimates for composite measure achievement (Panel E) are too unreliable to present for the “No insurance” group in 1999–2004 and 2017–2020, the “Medicaid” group for 1999–2004, and the “Other” group in 1999–2004 and 2005–2010; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

Line graphs showing control of A 1 C, blood pressure, L D L cholesterol, and being a non-smoker among adults with diagnosed diabetes significantly increased between 1999 and 2020 regardless of health insurance type.

TABLE 1.

Age-Standardized Trends in Prevalence of Diagnosed Diabetes Among Adults Age ≥20 Years, U.S., 2000–March 2020

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Total | 11.7 (0.4) | 13.4 (0.5) | 15.4 (0.5) | 17.6 (0.6)
Age (years)
20–44 | 2.2 (0.2) | 2.5 (0.2) | 3.1 (0.2) | 3.1 (0.3)
45–64 | 9.3 (0.5) | 10.8 (0.6) | 13.0 (0.6) | 14.8 (0.9)
≥65 | 16.5 (0.8) | 18.9 (0.7) | 21.0 (0.9) | 24.2 (1.1)
Race or ethnicity
Non-Hispanic White | 10.0 (0.5) | 11.1 (0.6) | 12.9 (0.5) | 15.4 (0.8)
Non-Hispanic Black | 19.2 (1.0) | 24.0 (0.8) | 24.0 (0.8) | 22.8 (1.3)
Hispanic | 15.8 (1.2) | 20.5 (1.1) | 22.6 (1.1) | 23.2 (1.1)
Mexican American* | 19.0 (0.7) | 21.4 (1.0) | 25.3 (1.4) | 27.6 (2.3)
Non-Hispanic Asian | ^†^ | ^†^ | 19.6 (1.4) | 20.6 (1.5)
Other | 16.0 (1.8) | 19.2 (1.7) | 20.3 (2.1) | 22.0 (1.2)
Insurance status
No insurance | 12.4 (3.1) | 10.8 (1.7) | 15.6 (2.5) | 19.1 (4.4)
Any insurance | 11.6 (0.4) | 13.5 (0.5) | 15.5 (0.6) | 17.8 (0.7)
Medicaid | 22.2 (2.2) | 24.5 (1.6) | 26.5 (1.5) | 26.5 (2.3)
Medicare/Medi-Gap^‡^ | 19.9 (1.5) | 23.1 (1.9) | 21.6 (1.3) | 24.4 (1.6)
Private | 10.0 (0.5) | 12.1 (0.6) | 13.5 (0.7) | 15.6 (0.8)
Other^§^ | 17.1 (1.9) | 16.3 (1.6) | 18.5 (1.9) | 19.4 (1.5)

All data are self-reported. Estimates are age-standardized to the NHANES 2017–2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Mexican American is a subset of Hispanic.

† Non-Hispanic Asian race/ethnicity data were not collected.

‡ Medi-Gap was not included in the NHANES 1999–2004.

§ Other insurance includes a state-sponsored plan or other government plan.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2000–March 2020

TABLE 2.

Characteristics of Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Age (years)
Mean (SE) | 59.2 (0.5) | 59.5 (0.5) | 59.9 (0.3) | 61.1 (0.7)
20–44 | 16.1 (1.3) | 14.3 (1.2) | 13.9 (0.7) | 11.7 (1.3)
45–64 | 43.5 (1.7) | 46.2 (1.2) | 46.5 (1.5) | 44.3 (2.0)
≥65 | 40.3 (1.9) | 39.5 (1.5) | 39.6 (1.2) | 44.0 (2.7)
Duration of diagnosed diabetes (years)
Mean (SE) | 12.9 (0.6) | 10.8 (0.3) | 11.6 (0.3) | 13.0 (0.5)
0–<5 | 36.3 (1.7) | 33.4 (1.5) | 29.2 (1.0) | 25.7 (1.5)
5–15 | 34.9 (1.5) | 41.2 (1.3) | 40.1 (1.2) | 38.3 (1.9)
≥15 | 28.8 (1.5) | 25.4 (1.2) | 30.7 (1.0) | 36.0 (1.8)
Sex
Men | 48.3 (1.4) | 47.8 (1.8) | 51.3 (1.3) | 53.8 (2.5)
Women | 51.7 (1.4) | 52.2 (1.8) | 48.7 (1.3) | 46.2 (2.5)
Race or ethnicity
Non-Hispanic White | 63.3 (2.8) | 61.4 (2.9) | 59.2 (2.5) | 60.2 (3.0)
Non-Hispanic Black | 16.2 (1.9) | 18.2 (1.8) | 15.6 (1.7) | 12.7 (2.0)
Hispanic | 13.8 (2.6) | 13.5 (1.8) | 16.1 (2.0) | 15.8 (1.8)
Mexican American* | 7.2 (1.3) | 8.5 (1.4) | 10.1 (1.8) | 9.2 (1.4)
Non-Hispanic Asian | ^†^ | ^†^ | 5.4 (0.7) | 5.8 (0.8)
Other | 13.4 (2.3) | 11.9 (1.3) | 9.7 (1.0) | 12.1 (1.1)
BMI (kg/m^2^)
Mean (SE) | 32.0 (0.4) | 32.9 (0.2) | 33.0 (0.2) | 33.1 (0.4)
<18.5 | 0.2 (0.1) | 0.3 (0.2) | 0.5 (0.2) | 0.4 (0.2)
18.5–24.9 | 16.4 (1.8) | 13.0 (0.8) | 11.4 (1.0) | 9.9 (1.1)
25.0–29.9 | 29.4 (1.9) | 25.9 (1.4) | 26.7 (1.2) | 26.9 (1.5)
30.0–34.9 | 23.6 (1.5) | 27.3 (1.4) | 29.0 (1.5) | 29.2 (1.9)
35.0–39.9 | 16.7 (1.4) | 17.8 (1.2) | 16.0 (0.9) | 17.8 (1.8)
>40.0 | 13.7 (1.4) | 15.5 (1.0) | 16.5 (1.1) | 15.9 (1.8)
Education level
High school or less | 34.6 (1.6) | 29.8 (1.1) | 23.2 (1.7) | 16.5 (1.4)
Some college | 25.0 (1.6) | 25.1 (1.8) | 23.6 (1.4) | 32.5 (2.6)
College graduate | 40.4 (1.9) | 45.1 (2.0) | 53.2 (1.8) | 51.0 (2.3)
Family poverty income (FPL) ratio
<130% of FPL | 29.0 (2.4) | 24.4 (1.4) | 28.8 (1.7) | 20.9 (1.7)
130%–349% of FPL | 41.7 (2.2) | 43.1 (1.7) | 38.5 (1.6) | 40.6 (3.6)
≥350% of FPL | 29.3 (2.0) | 32.5 (1.7) | 32.7 (2.0) | 38.5 (3.6)
Insurance status
No insurance | 10.3 (1.0) | 10.9 (1.0) | 10.2 (0.7) | 6.6 (1.1)
Any insurance | 89.7 (1.0) | 89.1 (1.0) | 89.8 (0.7) | 93.4 (1.1)
Medicaid | 10.0 (1.2) | 9.7 (0.9) | 13.1 (1.2) | 13.5 (1.2)
Medicare/Medi-Gap^‡^ | 42.9 (2.1) | 40.9 (1.6) | 39.7 (1.2) | 47.8 (2.8)
Private | 56.2 (1.8) | 57.6 (1.8) | 53.8 (1.8) | 53.4 (2.3)
Other^§^ | 8.6 (1.1) | 5.4 (0.6) | 7.8 (0.8) | 15.4 (1.5)

All data are self-reported, except BMI, which was determined using height and weight measured during an in-person physical exam. BMI, body mass index; SE, standard error.

* Mexican American is a subset of Hispanic.

† Non-Hispanic Asian race/ethnicity data were not collected.

‡ Medi-Gap was not included in the NHANES 1999–2004.

§ Other insurance includes a state-sponsored plan or other government plan.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 3.

Age-Standardized Trends in Risk Factor Control and Adherence to Preventive Measures Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

RISK FACTOR OR PRACTICE | PERCENT (STANDARD ERROR)
RISK FACTOR OR PRACTICE | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Risk Factors
A1C (%)
>9.0 | 15.2 (1.4) | 12.2 (0.8) | 14.4 (1.0) | 12.9 (1.4)
<8.0 | 71.1 (1.7) | 78.6 (1.3) | 72.3 (1.4) | 75.6 (2.3)
<7.0 | 49.6 (2.2) | 54.4 (1.9) | 51.2 (1.6) | 52.7 (3.2)
Blood pressure (mmHg)
<130/80 | 41.2 (2.2) | 49.7 (1.6) | 49.2 (1.5) | 47.6 (2.5)
<140/90 | 65.7 (1.6) | 70.3 (1.3) | 73.1 (1.5) | 71.5 (2.7)
LDL cholesterol
<100 mg/dL without ASCVD | 27.7 (2.9) | 38.7 (2.2) | 40.0 (2.7) | 46.4 (4.3)
<70 mg/dL with ASCVD | 3.2 (0.9) | 7.2 (1.0) | 7.0 (0.9) | 9.3 (2.0)
<100 mg/dL without ASCVD or <70 mg/dL with ASCVD | 32.3 (2.8) | 46.7 (2.2) | 48.0 (2.6) | 56.1 (3.3)
Smoking status*
Never smoker | 47.0 (1.9) | 50.0 (1.3) | 48.8 (1.2) | 49.4 (2.8)
Former smoker | 34.2 (1.4) | 34.3 (1.0) | 36.5 (1.1) | 36.1 (2.9)
Current smoker | 18.8 (1.2) | 15.8 (0.9) | 14.8 (1.0) | 14.6 (1.2)
Composite measure achievement of A1C, blood pressure, LDL cholesterol, smoking status^†^ | 13.2 (2.2) | 24.3 (1.7) | 21.4 (2.2) | 25.3 (3.9)
Preventive Measures
Screenings
Lipid testing^‡^ | 86.8 (1.1) | 91.0 (0.7) | 90.8 (0.8) | 88.9 (1.0)
Routine examinations
Eye exam | N/A | 78.0 (1.2) | 80.3 (1.3) | 82.9 (1.3)
Dental exam | 29.1(1.7) | N/A | 37.6 (2.2) | 40.5 (2.3)
Foot exam^§^ | N/A | 71.7 (1.3) | 72.1 (1.6) | 73.9 (1.7)
Health Behavior Measures
Self-glucose monitoring^ǁ^
More than once daily | N/A | 60.3 (2.7) | 61.8 (3.3) | 57.1 (3.3)
Physical activity^¶^
Met physical activity standards | N/A | 35.6 (1.4) | 38.8 (1.8) | 47.4 (2.4)
Insufficiently active | N/A | 14.4 (1.2) | 16.2 (1.3) | 15.9 (1.7)
Inactive | N/A | 50.0 (1.5) | 44.9 (1.8) | 36.8 (1.8)
Practicing weight control^#^ | 38.8 (2.2) | 41.4 (2.0) | 46.6 (1.8) | 46.5 (1.9)
Practicing diabetic diet | N/A | 62.6 (2.5) | 55.9 (2.8) | 57.5 (4.9)
Healthcare Utilization
Healthcare visit >1 time in past year | 91.2 (0.8) | 93.0 (0.7) | 90.2 (0.7) | 90.4 (1.0)
Seen diabetes specialist in past 2 years | N/A | 65.8 (1.9) | 62.1 (1.6) | 52.8 (2.5)

Diabetes status is self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥ 65 years. Conversion formulas for A1C and LDL cholesterol are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein; N/A, not applicable, data are not available in these survey periods.

* Self-reported.

† A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

‡ Self-report of a cholesterol test in the past 1–2 years

§ Foot exam is defined as a foot examination conducted by a health professional within the past 12 months, assessing the frequency of checks for sores or irritations. Self-reported.

ǁ Among those taking insulin

¶ Physical activity standards are defined as ≥150 minutes of moderate or ≥75 minutes of vigorous leisure-time or work-related physical activity per week; physical activity is self-reported.

# Self-report of trying to lose weight in past year

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 4.

Age-Standardized Trends in Vaccinations Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 2000–2020

VACCINATION | PERCENT (STANDARD ERROR)
VACCINATION | 2000 | 2005 | 2010 | 2015 | 2020
Annual influenza* | 54.0 (1.2) | 50.5 (1.1) | 60.4 (1.9) | 62.2 (1.0) | 63.4 (1.1)
Pneumococcal^†^ | 42.6 (1.2) | 47.1 (1.1) | 52.2 (1.1) | 53.7 (1.1) | 53.2 (1.0)

All data are self-reported. Estimates are age-sex-race/ethnicity standardized to the NHIS 2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Received a flu shot in the past 12 months.

† Ever received a pneumococcal vaccine.

SOURCE: National Health Interview Surveys (NHIS) 2000–2020

TABLE 5.

Age-Standardized Distributions of Medication Use Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

MEDICATION USE | PERCENT (STANDARD ERROR)
MEDICATION USE | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Glucose-lowering medications
Insulin | 19.2 (1.4) | 23.1 (1.1) | 27.2 (1.3) | 26.7 (1.4)
Biguanide (metformin) | 37.4 (1.7) | 48.9 (1.8) | 58.4 (1.3) | 60.2 (1.8)
Sulfonylurea | 40.8 (1.7) | 36.3 (1.4) | 27.4 (1.5) | 25.3 (2.0)
DPP-4 inhibitors* | N/A | 4.8 (0.7) | 9.8 (0.9) | 13.3 (1.8)
GLP-1 receptor agonists^†^ | N/A | 1.4 (0.4) | 3.8 (0.6) | 5.1 (0.7)
SGLT2 inhibitors^‡^ | N/A | N/A | 1.0 (0.3) | 7.2 (1.4)
Thiazolidinediones (TZD) | 17.0 (1.1) | 19.4 (1.2) | 5.1 (0.7) | 4.9 (0.9)
Any glucose-lowering medication | 75.7 (1.5) | 81.3 (1.4) | 83.3 (1.0) | 83.1 (1.3)
Blood pressure-lowering medications
ACEi or ARB | 44.5 (1.3) | 57.9 (1.6) | 61.0 (1.5) | 58.3 (1.7)
Calcium channel blocker (CCB) | 21.9 (1.4) | 19.6 (1.1) | 20.0 (1.2) | 22.1 (1.7)
Beta blockers | 19.5 (1.4) | 31.1 (1.4) | 31.1 (1.4) | 32.9 (1.9)
Other | 37.8 (1.7) | 41.5 (1.6) | 38.9 (1.3) | 35.6 (2.6)
Any blood pressure-lowering medication | 65.7 (1.4) | 74.6 (1.5) | 75.7 (1.2) | 75.2 (1.9)
Lipid-lowering medications
Statin (among age ≥40 years) | 33.4 (1.7) | 52.9 (1.3) | 57.8 (1.6) | 59.4 (2.3)
Other | 5.9 (0.9) | 15.5 (1.4) | 11.0 (0.9) | 8.5 (1.2)
Any lipid-lowering medication | 36.2 (1.6) | 56.3 (1.3) | 61.3 (1.3) | 60.7 (1.9)

Diabetes status and medication use are self-reported. Estimates are age-sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. A1C, glycated hemoglobin; ACEi, angiotensin-converting enzyme inhibitor; ARB, angiotensin II receptor blocker; FDA, U.S. Food and Drug Administration; N/A, not applicable.

* DPP-4 (dipeptidyl peptidase-4) inhibitors, FDA approval in 2006

† GLP-1 (glucagon-like peptide-1) receptor agonists, FDA approval in 2005

‡ SGLT2 (sodium-glucose cotransporter-2) inhibitors, FDA approval in 2013

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 6.

Trends in Use of Insulin and Other Glucose-Lowering Medications Among Adults Age ≥20 Years With Diagnosed Diabetes, by Age, U.S., 1999–March 2020

AGE (YEARS) | PERCENT (STANDARD ERROR)
AGE (YEARS) | Insulin Only | | | | Insulin With Other Oral Glucose-Lowering Medications*
AGE (YEARS) | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Total | 19.3 (1.4) | 23.5 (1.2) | 27.3 (1.3) | 26.7 (1.4) | 56.0 (1.6) | 57.5 (1.8) | 55.5 (1.7) | 56.4 (1.6)
20–44 | 21.1 (3.9) | 30.7 (4.1) | 31.4 (3.2) | 35.3 (7.6) | 46.3 (4.6) | 44.1 (3.2) | 39.2 (3.3) | 38.9 (6.8)
45–64 | 18.2 (2.1) | 24.5 (1.8) | 26.4 (1.9) | 23.9 (3.0) | 58.7 (2.7) | 56.9 (2.3) | 56.4 (2.9) | 60.6 (4.1)
≥65 | 19.7 (1.8) | 19.8 (1.7) | 26.9 (1.9) | 27.2 (1.9) | 56.9 (2.2) | 63.1 (2.2) | 60.2 (1.8) | 56.8 (2.5)

Diabetes status and medication use are self-reported. Estimates are sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using race/ethnicity groups non-Hispanic White, non-Hispanic Black, Hispanic, and non-Hispanic Asian.

* Other glucose-lowering medications include: biguanide (metformin), sulfonylurea, alpha-glucosidases inhibitors, meglitinides, antidiabetic combinations, amylin analogs, dipeptidyl peptidase-4 (DPP-4) inhibitors, glucagon-like peptide-1 (GLP-1) receptor agonists, sodium-glucose cotransporter-2 (SGLT2) inhibitors, and thiazolidinediones (TZD).

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 7.

Age-Standardized Trends in Medication Use Based on Comorbidities Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

COMORBIDITY AND MEDICATION | PERCENT (STANDARD ERROR)
COMORBIDITY AND MEDICATION | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
ASCVD
Aspirin or antiplatelet | 44.5 (4.2) | * | 73.1 (3.0) | 80.7 (2.6)
GLP-1 receptor agonist^†^ | N/A | 1.3 (0.7) | 2.7 (0.7) | 4.2 (1.2)
SGLT2 inhibitor^‡^ | N/A | N/A | 0.8 (0.2) | 9.2 (2.2)
Statin | 54.5 (5.3) | 63.3 (3.8) | 71.3 (2.8) | 73.6 (3.5)
Heart failure^§^
GLP-1 receptor agonist^†^ | N/A | ^3^ | 3.4 (1.4)^2^ | 6.2 (2.1)^1^
SGLT2 inhibitor^‡^ | N/A | N/A | ^3^ | ^3^
Chronic kidney disease^ǁ^
ACEi or ARB | 51.1 (6.0) | 68.2 (4.7) | 65.5 (5.2) | 60.5 (4.6)
SGLT2 inhibitor^‡^ | N/A | N/A | ^3^ | ^3^
BMI ≥27.0 kg/m^2^
GLP-1 receptor agonist | N/A | 1.8 (0.5) | 4.6 (0.8) | 6.6 (1.1)

Diabetes status is self-reported. Estimates are age-sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. ACEi, angiotensin-converting enzyme inhibitor; ARB, angiotensin II receptor blocker; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; BMI, body mass index; N/A, not applicable.

* Aspirin use data were not collected in 2005–2010.

† GLP-1 (glucagon-like peptide-1) receptor agonists, FDA approval in 2005

‡ SGLT2 (sodium-glucose cotransporter-2) inhibitors, FDA approval in 2013

§ Self-reported.

ǁ Chronic kidney disease is defined as estimated glomerular filtration rate (eGFR) <60 mL/min/1.73 m2. eGFR is calculated using the CKD-EPI formula: eGFR =142*min(standardized Scr/K, 1)α *max(standardized Scr/K, 1)-1.200 *0.993^Age^ *1.012 [if female].

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 8.

Age-Standardized Trends in the Prevalence of Complications Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

COMPLICATION | PERCENT (STANDARD ERROR)
COMPLICATION | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Any cardiovascular disease* | 25.1 (1.6) | 25.3 (1.1) | 24.3 (1.2) | 25.7 (2.0)
Coronary heart disease | 13.3 (1.3) | 12.7 (0.7) | 12.3 (0.8) | 14.8 (2.5)
Congestive heart failure | 11.2 (1.0) | 11.3 (0.8) | 10.6 (0.9) | 9.6 (1.1)
Stroke | 8.8 (0.9) | 11.2 (0.9) | 8.9 (0.8) | 10.9 (1.2)
Any chronic kidney disease^†^ | 25.1 (1.2) | 24.5 (1.5) | 25.0 (1.3) | 20.8 (1.3)
Urinary albumin ≥300 mg/g creatinine | 8.8 (1.0) | 7.4 (0.8) | 7.9 (1.0) | 6.9 (0.8)
eGFR <30 mL/min/1.73 m^2^ | 2.6 (0.5) | 2.9 (0.3) | 3.4 (0.5) | 1.8 (0.3)
eGFR <60 mL/min/1.73 m^2^ | 19.6 (1.2) | 19.8 (1.3) | 20.8 (1.1) | 16.3 (1.2)
Retinopathy | 25.1 (1.7) | 20.8 (1.0) | 18.3 (1.3) | 19.6 (1.4)

Diabetes status, cardiovascular disease, and retinopathy are self-reported. Estimates are age-sex-race/ethnicity standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. eGFR, estimated glomerular filtration rate.

* Includes coronary heart disease, congestive heart failure, and stroke.

† Any chronic kidney disease includes eGFR <60 mL/min/1.73 m^2^ or urine albumin to creatinine ratio (ACR) ≥300 mg/mmol. eGFR is calculated using the CKD-EPI formula: eGFR =142*min (standardized Scr/K, 1)α*max(standardized Scr/K, 1)-1.200 *0.993^Age^ *1.012 [if female].

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 9.

Age-Standardized Trends in Incidence of Inpatient Hospital Discharges for Selected Diabetes-Related Conditions Among Adults Age ≥20 Years With Diabetes, U.S., 2000–2020

HOSPITAL DISCHARGE | INCIDENCE PER 100 PERSONS (STANDARD ERROR)
HOSPITAL DISCHARGE | 2000 | 2005 | 2010 | 2015 | 2020
Lower extremity amputation* | 1.11 (0.02) | 0.73 (0.02) | 0.61 (0.01) | 0.76 (0.01) | 1.30 (0.01)
Ketoacidosis | 2.15 (0.04) | 1.99 (0.03) | 2.20 (0.04) | 2.73 (0.02) | 4.15 (0.03)
Hyperosmolar hyperglycemic syndrome | 0.42 (0.01) | 0.34 (0.01) | 0.45 (0.01) | 0.57 (0.01) | 0.59 (0.01)
Hypoglycemia^†^ | 0.08 (0.00) | 0.09 (0.00) | 0.10 (0.00) | 0.22 (0.00) | 0.57 (0.01)
Diabetes-related coma | 0.16 (0.01) | 0.12 (0.00) | 0.08 (0.00) | 0.06 (0.00) | 0.03 (0.00)

Diabetes is defined by ICD-9 code (250, 357.2, 362.0, 366.41, 648.0, and 775) or ICD-10 code (E10 for type 1 diabetes and E11 for type 2 diabetes). Types of hospital discharges are based on ICD-9 and ICD-10 codes, any diagnosis code. Estimates are age-sex-race/ethnicity standardized to the HCUP 2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. ICD-9/10, International Classification of Diseases, 9th/10th Revision.

* Lower extremity amputation includes amputations at the hip, above the knee, below the knee, and at the foot level.

† Hypoglycemia is defined as diagnoses related to hypoglycemic conditions, including diabetes-related or drug-induced hypoglycemia.

SOURCE: Healthcare Cost and Utilization Project (HCUP)-National Inpatient Sample 2000–2020

TABLE 10.

Trends in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures Among Adults Age ≥20 Years With Diagnosed Diabetes, by Age, U.S., 1999–March 2020

AGE (YEARS) | PERCENT (STANDARD ERROR)
AGE (YEARS) | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Risk Factors
| A1C <8.0% | | | | Blood Pressure <140/90 mmHg | | | | LDL Cholesterol <100 mg/dL Without ASCVD or <70 mg/dL With ASCVD
20–44 | 60.0 (5.4) | 59.9 (4.1) | 62.6 (3.7) | 69.7 (6.7) | 80.3 (4.3) | 81.9 (3.3) | 84.0 (3.1) | 83.5 (7.7) | 40.2 (7.2) | 47.1 (6.9) | 37.2 (7.1) | 31.2 (6.4)
45–64 | 65.1 (2.8) | 75.7 (1.9) | 66.9 (2.2) | 70.2 (4.8) | 74.0 (2.3) | 75.5 (2.1) | 78.2 (1.5) | 73.2 (4.2) | 27.6 (4.2) | 44.9 (3.6) | 43.8 (4.2) | 51.7 (6.0)
≥65 | 80.2 (2.3) | 86.5 (1.3) | 80.3 (1.8) | 82.6 (1.6) | 53.5 (2.8) | 61.9 (2.2) | 65.2 (2.4) | 66.5 (3.4) | 35.0 (5.0) | 48.5 (3.1) | 55.2 (3.0) | 67.1 (3.7)
| Smoking Status: Not Current Smoker | | | | Composite Measure Achievement of A1C, Blood Pressure, LDL Cholesterol, Smoking Status*
20–44 | 65.3 (4.2) | 74.0 (3.8) | 78.2 (3.0) | 78.8 (5.9) | 23.1 (5.6) | 14.5 (5.0) | 14.7 (3.9) | 14.3 (4.0)
45–64 | 74.0 (2.3) | 79.1 (1.6) | 79.1 (1.8) | 80.2 (2.6) | 10.4 (2.7) | 25.4 (3.2) | 20.3 (3.8) | 20.0 (5.4)
≥65 | 92.6 (1.4) | 92.2 (0.7) | 93.3 (1.0) | 92.4 (1.8) | 13.3 (3.3) | 25.8 (2.2) | 24.3 (2.6) | 33.5 (5.9)
Preventive Measures
| Preventive Screenings: Lipid Testing^†^ | | | | Annual Examinations: Eye Exam | | | | Annual Examinations: Dental Exam
20–44 | 76.9 (4.1) | 77.3 (3.1) | 79.2 (3.5) | 73.9 (5.7) | N/A | 66.4 (3.9) | 66.1 (3.4) | 77.1 (6.4) | 28.3 (4.7) | N/A | 34.7 (4.1) | 43.8 (6.4)
45–64 | 84.7 (2.0) | 89.9 (1.3) | 91.3 (1.3) | 88.0 (2.0) | N/A | 74.2 (1.9) | 77.6 (2.2) | 77.9 (1.9) | 32.3 (2.3) | N/A | 36.7 (2.8) | 40.8 (3.3)
≥65 | 91.5 (1.2) | 95.8 (0.7) | 93.3 (0.9) | 93.8 (1.4) | N/A | 85.0 (1.5) | 86.8 (1.5) | 89.5 (0.9) | 26.1 (2.3) | N/A | 39.2 (3.7) | 39.3 (2.1)
| Annual Examinations: Foot Exam^‡^
20–44 | N/A | 65.2 (4.3) | 60.3 (4.4) | 66.9 (7.4)
45–64 | N/A | 68.8 (2.0) | 70.6 (2.3) | 69.5 (3.3)
≥65 | N/A | 76.5 (1.7) | 76.8 (2.1) | 80.3 (2.1)
Health Behavior Measures
| Self-Glucose Monitoring More Than Once Daily | | | | Physical Activity: Met Physical Activity Recommendations^§^ | | | | Practicing Weight Control^ǁ^
20–44 | N/A | 78.6 (5.1) | 60.8 (6.2) | 76.0 (9.1) | N/A | 51.7 (5.2) | 48.9 (3.9) | 55.1 (6.4) | 47.9 (6.1) | 49.7 (5.1) | 54.3 (4.0) | 61.5 (7.1)
45–64 | N/A | 61.2 (3.4) | 56.8 (5.2) | 53.4 (5.6) | N/A | 36.7 (2.7) | 42.5 (2.2) | 52.6 (3.1) | 46.1 (3.4) | 47.8 (2.8) | 53.6 (3.1) | 47.8 (4.2)
≥65 | N/A | 54.5 (4.2) | 67.1 (4.1) | 55.9 (4.6) | N/A | 30.2 (2.1) | 32.5 (2.9) | 40.0 (2.6) | 29.2 (2.1) | 32.7 (2.4) | 37.5 (2.5) | 41.2 (4.1)
| Healthcare Visit More Than Once in Past Year | | | | Seen Diabetes Specialist
20–44 | 91.5 (2.4) | 89.4 (1.9) | 83.0 (2.8) | 86.0 (3.9) | N/A | 79.9 (3.8) | 71.9 (4.7) | 61.6 (9.7)
45–64 | 87.4 (1.5) | 91.6 (1.2) | 87.0 (1.5) | 88.6 (2.1) | N/A | 66.1 (2.8) | 60.5 (2.3) | 56.7 (4.7)
≥65 | 94.8 (0.8) | 95.3 (0.8) | 95.5 (0.9) | 93.3 (1.0) | N/A | 61.9 (2.3) | 61.1 (2.6) | 46.6 (2.5)

Diabetes status is self-reported. Conversion formulas for A1C and LDL cholesterol are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein; N/A, not applicable, data are not available in these survey periods.

* A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

† Self-report of a cholesterol test in the past 1–2 years

‡ Foot exam is defined as a foot examination conducted by a health professional within the past 12 months, assessing the frequency of checks for sores or irritations. Self-reported.

§ Physical activity standards are defined as ≥150 minutes of moderate or ≥75 minutes of vigorous leisure-time or work-related physical activity per week; physical activity is self-reported.

ǁ Self-report of trying to lose weight in past year

SOURCE: National Health and Nutrition Examination Surveys 1999–March 2020

TABLE 11.

Trends in Vaccinations Among Adults Age ≥20 Years With Diagnosed Diabetes, by Age, U.S., 2000–2020

AGE (YEARS) | PERCENT (STANDARD ERROR)
AGE (YEARS) | Annual Influenza* | | | | | Pneumococcal, Ever^†^
AGE (YEARS) | 2000 | 2005 | 2010 | 2015 | 2020 | 2000 | 2005 | 2010 | 2015 | 2020
20–44 | 32.9 (3.4) | 29.6 (3.2) | 47.3 (5.3) | 40.9 (3.4) | 45.3 (4.0) | 20.5 (3.0) | 24.4 (2.9) | 24.4 (2.8) | 28.3 (3.5) | 21.8 (2.8)
45–64 | 44.2 (1.9) | 38.0 (1.6) | 55.5 (2.8) | 55.5 (1.8) | 54.8 (1.9) | 29.2 (1.7) | 33.9 (1.6) | 42.7 (1.6) | 42.1 (1.7) | 38.1 (1.8)
≥65 | 67.2 (1.9) | 65.9 (1.7) | 67.6 (2.5) | 72.8 (1.3) | 74.9 (1.4) | 59.1 (1.9) | 63.4 (1.7) | 66.8 (1.6) | 69.4 (1.5) | 73.2 (1.4)

All data are self-reported.

* Received a flu shot in the past 12 months.

† Ever received a pneumococcal vaccine.

SOURCE: National Health Interview Surveys (NHIS) 2000–2020

TABLE 12.

Age-Standardized Trends in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures Among Adults Age ≥20 Years With Diagnosed Diabetes, by Race and Ethnicity, U.S., 1999–March 2020

RACE OR ETHNICITY | PERCENT (STANDARD ERROR)
RACE OR ETHNICITY | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Risk Factors
| A1C <8.0% | | | | Blood Pressure <140/90 mmHg | | | | LDL Cholesterol <100 mg/dL Without ASCVD or <70 mg/dL With ASCVD
Non-Hispanic White | 74.4 (2.3) | 81.4 (1.6) | 75.0 (2.0) | 78.7 (4.1) | 68.6 (2.2) | 72.5 (2.0) | 75.0 (2.1) | 73.3 (4.5) | 33.4 (4.5) | 53.1 (3.4) | 48.7 (2.7) | 56.8 (3.7)
Non-Hispanic Black | 65.3 (2.5) | 72.2 (1.9) | 70.1 (2.2) | 67.5 (2.6) | 56.8 (2.8) | 63.2 (2.0) | 62.4 (2.1) | 54.5 (3.1) | 33.6 (5.3) | 30.8 (3.3) | 49.2 (3.9) | 57.5 (5.5)
All Hispanic | 66.0 (3.3) | 71.5 (2.7) | 64.1 (2.2) | 64.4 (3.8) | 65.9 (4.5) | 68.9 (2.2) | 72.9 (2.1) | 69.7 (3.4) | 24.5 (5.3) | 39.2 (4.2) | 44.8 (3.0) | 54.8 (5.1)
Mexican American* | 62.0 (2.4) | 70.2 (3.1) | 64.3 (3.0) | 66.7 (5.2) | 62.1 (2.7) | 68.1 (3.5) | 73.0 (3.1) | 69.4 (5.1) | 32.9 (4.2) | 40.5 (3.4) | 40.6 (3.5) | 52.6 (4.5)
Non-Hispanic Asian | N/A | N/A | 80.2 (2.1) | 81.6 (4.9) | N/A | N/A | 76.3 (3.7) | 75.8 (4.9) | N/A | N/A | 41.7 (3.7) | 52.2 (5.0)
| Smoking Status Not Current Smoker | | | | Composite Measure Achievement of A1C, Blood Pressure, LDL Cholesterol, Smoking Status^†^
Non-Hispanic White | 81.9 (1.8) | 83.6 (1.3) | 85.4 (1.6) | 85.0 (1.9) | 16.2 (3.3) | 29.1 (2.8) | 22.0 (3.3) | 26.5 (6.7)
Non-Hispanic Black | 78.3 (2.0) | 80.8 (1.8) | 82.8 (1.5) | 80.7 (1.8) | 14.1 (3.7) | 12.3 (2.0) | 16.4 (2.7) | 15.1 (4.0)
All Hispanic | 80.9 (3.2) | 87.4 (1.4) | 86.2 (1.2) | 91.1 (1.9) | 5.6 (1.8) | 18.9 (3.9) | 18.3 (2.4) | 22.3 (3.3)
Mexican American* | 82.4 (1.5) | 87.1 (1.7) | 85.6 (2.0) | 90.5 (2.5) | 6.9 (2.0) | 19.8 (4.1) | 18.8 (3.2) | 22.3 (5.3)
Non-Hispanic Asian | N/A | N/A | 95.1 (1.5) | 93.6 (1.7) | N/A | N/A | 40.2 (4.5) | 25.6 (5.1)
Preventive Measures
| Preventive Screenings: Lipid Testing^‡^ | | | | Annual Examinations: Eye Exam | | | | Annual Examinations: Dental Exam
Non-Hispanic White | 87.8 (1.5) | 94.5 (0.8) | 93.5 (1.2) | 89.5 (1.4) | N/A | 79.7 (1.5) | 83.0 (1.7) | 83.6 (2.4) | 31.1 (2.6) | N/A | 42.2 (3.2) | 41.0 (3.3)
Non-Hispanic Black | 83.5 (1.6) | 88.2 (1.3) | 88.5 (1.4) | 89.1 (2.7) | N/A | 81.9 (1.6) | 79.8 (2.3) | 80.5 (2.9) | 24.4 (2.3) | N/A | 31.5 (2.2) | 32.5 (2.9)
All Hispanic | 82.7 (2.7) | 79.4 (1.9) | 85.2 (1.3) | 84.6 (2.0) | N/A | 66.9 (3.2) | 70.9 (2.1) | 80.0 (2.8) | 22.3 (3.1) | N/A | 26.7 (2.7) | 40.8 (2.4)
Mexican American* | 79.6 (1.9) | 74.8 (2.3) | 88.1 (1.6) | 83.8 (2.3) | N/A | 63.2 (2.5) | 67.7 (3.0) | 81.7 (3.3) | 24.1 (2.8) | N/A | 25.4 (3.3) | 33.2 (2.9)
Non-Hispanic Asian | N/A | N/A | 88.5 (2.5) | 90.5 (2.3) | N/A | N/A | 76.5 (2.9) | 85.7 (2.4) | N/A | N/A | 40.6 (3.4) | 56.0 (4.1)
| Annual Examinations: Foot Exam^§^
Non-Hispanic White | N/A | 73.1 (1.9) | 74.4 (2.4) | 77.5 (2.3)
Non-Hispanic Black | N/A | 77.9 (1.7) | 75.5 (1.9) | 75.2 (2.6)
All Hispanic | N/A | 59.2 (2.6) | 62.9 (1.9) | 69.6 (3.5)
Mexican American* | N/A | 59.7 (2.9) | 64.4 (2.8) | 67.1 (4.0)
Non-Hispanic Asian | N/A | N/A | 65.4 (3.0) | 66.7 (3.7)
Health Behavior Measures
| Self-Glucose Monitoring More Than Once Daily | | | | Physical Activity: Met Physical Activity Recommendations^ǁ^ | | | | Practicing Weight Control^¶^
Non-Hispanic White | N/A | 64.3 (3.9) | 64.9 (5.3) | 57.2 (5.0) | N/A | 38.7 (2.1) | 40.5 (2.3) | 51.8 (3.4) | 40.6 (3.3) | 42.9 (3.2) | 50.9 (2.8) | 45.4 (3.5)
Non-Hispanic Black | N/A | 50.3 (4.1) | 58.1 (3.1) | 59.2 (3.5) | N/A | 24.0 (2.4) | 35.9 (2.1) | 39.2 (2.6) | 39.0 (2.8) | 40.0 (1.9) | 41.5 (2.1) | 40.0 (2.5)
All Hispanic | N/A | 48.8 (4.3) | 58.2 (4.1) | 65.1 (6.4) | N/A | 27.7 (2.8) | 35.6 (2.0) | 47.0 (3.6) | 32.1 (3.9) | 37.9 (3.4) | 40.6 (2.1) | 49.2 (3.7)
Mexican American* | N/A | 39.6 (6.0) | 57.0 (6.1) | 58.9 (8.3) | N/A | 30.5 (4.0) | 38.9 (2.8) | 48.0 (3.8) | 35.8 (3.3) | 33.2 (2.8) | 41.2 (2.8) | 49.6 (5.4)
Non-Hispanic Asian | N/A | N/A | 46.2 (7.7) | 38.1 (7.8) | N/A | N/A | 32.1 (2.7) | 33.8 (4.9) | N/A | N/A | 33.6 (2.6) | 43.5 (4.8)
| Healthcare Visit More Than Once in Past Year | | | | Seen Diabetes Specialist
Non-Hispanic White | 90.5 (1.2) | 94.9 (1.0) | 91.5 (1.3) | 92.2 (1.6) | N/A | 61.3 (2.4) | 56.2 (2.5) | 49.4 (3.7)
Non-Hispanic Black | 92.9 (1.6) | 94.2 (0.9) | 92.2 (1.0) | 88.9 (2.4) | N/A | 73.3 (2.2) | 72.7 (2.2) | 61.5 (3.3)
All Hispanic | 89.8 (2.2) | 85.5 (1.4) | 85.3 (1.3) | 86.7 (1.7) | N/A | 76.4 (2.5) | 70.6 (2.5) | 62.3 (3.7)
Mexican American* | 88.5 (2.1) | 84.7 (1.4) | 84.8 (1.6) | 85.2 (2.8) | N/A | 75.1 (2.9) | 71.2 (3.0) | 61.2 (4.9)
Non-Hispanic Asian | N/A | N/A | 84.4 (2.1) | 87.3 (3.1) | N/A | N/A | 73.9 (4.4) | 54.7 (8.7)

Diabetes status is self-reported. Estimates are age-and-sex standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; N/A, not applicable, data are not available in these survey periods.

* Mexican American is a subset of Hispanic.

† A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

‡ Self-report of a cholesterol test in the past 1–2 years

§ Foot exam is defined as a foot examination conducted by a health professional within the past 12 months, assessing the frequency of checks for sores or irritations. Self-reported.

ǁ Physical activity standards are defined as ≥150 minutes of moderate or ≥75 minutes of vigorous leisure-time or work-related physical activity per week; physical activity is self-reported.

¶ Self-report of trying to lose weight in past year

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 13.

Age-Standardized Trends in Vaccinations Among Adults Age ≥20 Years With Diagnosed Diabetes, by Race and Ethnicity, U.S., 2000–2020

RACE OR ETHNICITY | PERCENT (STANDARD ERROR)
RACE OR ETHNICITY | Annual Influenza* | | | | | Pneumococcal, Ever^†^
RACE OR ETHNICITY | 2000 | 2005 | 2010 | 2015 | 2020 | 2000 | 2005 | 2010 | 2015 | 2020
Non-Hispanic White | 56.9 (1.5) | 54.9 (1.3) | 65.0 (2.6) | 64.4 (1.5) | 67.6 (1.3) | 47.3 (1.5) | 52.6 (1.4) | 58.4 (1.5) | 59.2 (1.4) | 59.9 (1.3)
Non-Hispanic Black | 47.3 (2.9) | 36.4 (2.7) | 49.7 (3.9) | 53.8 (2.3) | 58.2 (2.9) | 32.7 (2.8) | 38.3 (2.6) | 43.9 (2.0) | 44.1 (2.4) | 49.1 (2.9)
Hispanic | 45.7 (3.4) | 39.2 (3.1) | 48.9 (3.9) | 57.1 (2.5) | 55.0 (3.2) | 25.2 (2.7) | 25.6 (3.1) | 35.5 (2.5) | 40.4 (2.6) | 36.6 (2.6)
Mexican American^‡^ | 42.5 (3.6) | 40.5 (4.0) | 51.2 (5.0) | 60.4 (3.0) | 54.2 (4.2) | 23.2 (3.4) | 28.4 (4.3) | 33.3 (3.4) | 41.7 (3.3) | 36.1 (3.7)
Non-Hispanic Asian | 43.0 (12.1) | 42.5 (6.7) | 61.2 (7.2) | 72.4 (4.2) | 61.9 (5.3) | 42.9 (11.0) | 31.8 (6.6) | 34.1 (3.7) | 46.3 (5.2) | 34.9 (4.5)

All data are self-reported. Race/ethnicity and duration of diabetes estimates are age-standardized to the NHIS 2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Received a flu shot in the past 12 months.

† Ever received a pneumococcal vaccine.

‡ Mexican American is a subset of Hispanic.

SOURCE: National Health Interview Surveys (NHIS) 2000–2020

TABLE 14.

Age-Standardized Trends in Prevalence of Diagnosed Diabetes Among Adults Age ≥20 Years, by Insurance Coverage, U.S., 1999–March 2020

INSURANCE STATUS | PERCENT (STANDARD ERROR)
INSURANCE STATUS | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
No insurance | 12.4 (3.1) | 10.8 (1.7) | 15.6 (2.5) | 19.1 (4.4)
Any insurance | 11.6 (0.4) | 13.5 (0.5) | 15.5 (0.6) | 17.8 (0.7)
Medicaid | 22.2 (2.2) | 24.5 (1.6) | 26.5 (1.5) | 26.5 (2.3)
Medicare/Medi-Gap* | 19.9 (1.5) | 23.1 (1.9) | 21.6 (1.3) | 24.4 (1.6)
Private | 10.0 (0.5) | 12.1 (0.6) | 13.5 (0.7) | 15.6 (0.8)
Other^†^ | 17.1 (1.9) | 16.3 (1.6) | 18.5 (1.9) | 19.4 (1.5)

All data are self-reported. Estimates are age-standardized to the NHANES 2017–2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Medi-Gap was not included in the NHANES 1999–2004.

† Other insurance includes a state-sponsored plan or other government plan.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 15.

Age-Standardized Trends in Risk Factor Control and Adherence to Preventive Measures and Health Behavior Measures Among Adults Age ≥20 Years With Diagnosed Diabetes, by Insurance Status, U.S., 1999–March 2020

INSURANCE STATUS | PERCENT (STANDARD ERROR)
INSURANCE STATUS | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020 | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Risk Factors
| A1C <8.0% | | | | Blood Pressure <140/90 mmHg | | | | LDL Cholesterol <100 mg/dL Without ASCVD or <70 mg/dL With ASCVD
No insurance | 56.3 (6.8) | 68.1 (4.7) | 58.4 (5.9) | 69.4 (4.2) | 50.8 (5.5) | 62.7 (6.9) | 75.6 (4.3) | 80.7 (5.1) | 40.1 (16.9) | 48.8 (6.5) | 59.2 (3.8) | 14.4 (5.3)^1^
Any insurance | 72.5 (1.8) | 79.7 (1.4) | 73.4 (1.5) | 76.6 (2.6) | 67.0 (1.7) | 71.1 (1.5) | 73.1 (1.5) | 71.3 (2.7) | 32.7 (2.9) | 48.6 (2.5) | 48.3 (2.8) | 57.8 (3.6)
Medicaid | 66.4 (4.2) | 73.3 (3.0) | 72.4 (3.1) | 73.2 (5.2) | 61.5 (5.3) | 68.3 (3.4) | 70.4 (3.1) | 63.8 (4.0) | 32.0 (9.2) | 42.3 (6.0) | 45.9 (5.5) | 50.5 (4.7)
Medicare/Medi-Gap* | 74.5 (4.4) | 80.5 (2.3) | 78.8 (2.6) | 74.2 (2.8) | 67.3 (2.5) | 69.1 (3.6) | 70.6 (3.4) | 75.3 (2.9) | 28.6 (5.9) | 32.0 (3.9) | 51.5 (5.4) | 59.8 (5.1)
Private | 73.1 (2.1) | 81.0 (1.8) | 72.7 (1.9) | 77.0 (3.4) | 68.8 (2.2) | 71.0 (2.0) | 76.0 (2.0) | 69.2 (3.8) | 32.7 (3.5) | 52.6 (2.7) | 51.0 (3.7) | 59.3 (4.7)
Other^†^ | 73.3 (5.5) | 80.6 (4.7) | 80.0 (4.1) | 78.2 (3.3) | 74.1 (6.5) | 71.7 (7.1) | 72.0 (4.6) | 73.8 (3.7) | 33.0 (3.5) | 35.1 (7.2) | 42.7 (7.0) | 56.7 (6.9)
| Smoking Status Not Current Smoker | | | | Composite Measure Achievement of A1C, Blood Pressure, LDL Cholesterol, Smoking Status^‡^
No insurance | 75.6 (3.8) | 82.5 (3.3) | 79.3 (3.5) | 83.3 (3.4) | ^3^ | 20.7 (9.4) ^2^ | 13.1 (4.5) ^1^ | ^3^
Any insurance | 82.3 (1.4) | 84.4 (1.0) | 86.0 (1.1) | 85.8 (1.1) | 13.9 (2.4) | 25.5 (2.0) | 21.7 (2.4) | 25.9 (3.8)
Medicaid | 76.0 (4.1) | 73.5 (2.8) | 81.4 (2.7) | 76.6 (4.7) | ^3^ | 12.0 (4.0) ^1^ | 12.9 (4.0) ^1^ | 18.8 (6.6) ^1^
Medicare/Medi-Gap* | 78.6 (4.2) | 80.7 (2.6) | 81.3 (3.0) | 77.3 (3.3) | 7.9 (2.0) | 15.7 (3.4) | 20.3 (4.6) | 23.7 (4.3)
Private | 84.6 (1.7) | 86.6 (1.2) | 87.0 (1.4) | 89.3 (1.4) | 15.8 (2.7) | 29.6 (2.3) | 22.7 (3.1) | 23.0 (4.5)
Other^†^ | 72.8 (5.6) | 81.9 (4.5) | 87.5 (2.2) | 86.7 (2.9) | ^3^ | ^3^ | 20.9 (6.4) ^1^ | 31.8 (7.3)
Preventive Measures
| Preventive Screenings: Lipid Testing^§^ | | | | Annual Examinations: Eye Exam | | | | Annual Examinations: Dental Exam
No insurance | 73.6 (3.7) | 72.7 (4.9) | 65.2 (6.1) | 70.4 (3.7) | N/A | 46.6 (6.4) | 61.9 (5.6) | 64.1 (6.0) | 9.9 (3.1) | N/A | 15.7 (3.8) | 33.0 (9.0)
Any insurance | 89.0 (1.2) | 92.9 (0.7) | 93.0 (0.7) | 91.1 (1.0) | N/A | 81.1 (1.3) | 82.7 (1.4) | 84.7 (1.4) | 31.1 (1.9) | N/A | 39.5 (2.3) | 41.6 (2.5)
Medicaid | 83.9 (5.0) | 88.9 (2.0) | 87.1 (1.6) | 90.2 (2.3) | N/A | 81.8 (2.6) | 80.0 (2.2) | 82.1 (3.4) | 9.5 (2.9) | N/A | 22.1 (3.2) | 22.8 (2.9)
Medicare/Medi-Gap* | 90.5 (2.5) | 92.3 (2.0) | 91.9 (1.8) | 92.4 (2.1) | N/A | 80.9 (2.5) | 83.7 (2.9) | 85.8 (3.1) | 21.0 (2.7) | N/A | 31.3 (3.5) | 28.9 (2.0)
Private | 90.0 (1.3) | 94.2 (0.9) | 94.6 (1.0) | 92.1 (1.6) | N/A | 83.3 (1.5) | 84.5 (1.8) | 83.7 (1.8) | 36.0 (2.2) | N/A | 47.8 (3.0) | 47.8 (3.4)
Other^†^ | 96.3 (1.7) | 91.1 (3.0) | 91.8 (1.8) | 90.2 (2.3) | N/A | 74.5 (5.0) | 79.2 (4.7) | 91.3 (2.0) | 24.6 (5.7) | N/A | 27.9 (6.3) | 41.1 (4.1)
| Annual Examinations:; Foot Exam^‖^
No insurance | N/A | 48.1 (6.8) | 50.6 (5.4) | 55.6 (6.5)
Any insurance | N/A | 73.8 (1.4) | 74.5 (1.6) | 75.8 (1.7)
Medicaid | N/A | 74.3 (3.8) | 78.5 (2.8) | 75.6 (3.9)
Medicare/Medi-Gap* | N/A | 73.1 (3.7) | 81.5 (2.2) | 69.9 (3.9)
Private | N/A | 73.6 (1.8) | 74.7 (2.3) | 76.8 (2.2)
Other^†^ | N/A | 73.0 (5.0) | 70.6 (5.5) | 77.5 (3.8)
Health Behavior Measures
| Self-Glucose Monitoring More Than Once Daily | | | | Physical Activity: Met Physical Activity Recommendations^¶^ | | | | Practicing Weight Control^#^
No insurance | N/A | 30.3 (6.6) | 50.4 (10.0) | 53.2 (9.6) | N/A | 23.2 (3.4) | 46.1 (5.5) | 45.6 (9.0) | 31.7 (10.9) | 27.0 (6.0) | 50.9 (6.0) | 39.1 (10.9)
Any insurance | N/A | 62.0 (2.7) | 62.7 (3.5) | 57.7 (3.4) | N/A | 35.9 (1.5) | 38.2 (1.9) | 47.7 (2.4) | 40.4 (2.2) | 43.0 (2.1) | 47.2 (2.0) | 47.3 (1.8)
Medicaid | N/A | 52.5 (6.5) | 64.7 (5.1) | 54.5 (7.9) | N/A | 15.3 (3.6) | 27.4 (2.7) | 33.3 (4.4) | 38.4 (4.5) | 33.8 (3.9) | 37.4 (3.5) | 39.5 (5.0)
Medicare/Medi-Gap* | N/A | 63.3 (5.0) | 68.6 (3.5) | 57.0 (4.1) | N/A | 21.3 (2.5) | 26.1 (2.7) | 41.8 (4.2) | 41.1 (4.6) | 43.8 (3.7) | 39.3 (3.2) | 52.6 (3.3)
Private | N/A | 61.1 (4.0) | 62.7 (4.8) | 60.8 (5.4) | N/A | 40.7 (1.7) | 43.1 (2.8) | 50.8 (3.5) | 42.4 (2.4) | 45.0 (2.6) | 50.8 (2.9) | 50.1 (2.6)
Other^†^ | N/A | 39.5 (9.3) | 67.4 (8.8) | 57.3 (6.6) | N/A | 46.9 (6.8) | 33.8 (5.2) | 39.1 (4.2) | 37.9 (6.8) | 45.2 (7.3) | 44.3 (6.1) | 38.7 (4.9)
| Healthcare Visit More Than Once in Past Year | | | | Seen Diabetes Specialist
No insurance | 81.7 (4.2) | 86.6 (1.7) | 72.9 (3.5) | 75.4 (3.6) | N/A | 85.3 (2.2) | 66.4 (8.0) | 57.0 (7.5)
Any insurance | 92.6 (0.9) | 94.4 (0.7) | 92.4 (0.9) | 92.0 (1.1) | N/A | 65.0 (2.0) | 61.5 (1.7) | 52.8 (2.7)
Medicaid | 91.5 (3.6) | 97.1 (1.0) | 95.4 (1.0) | 94.2 (1.5) | N/A | 71.1 (4.8) | 70.8 (3.6) | 50.0 (5.9)
Medicare/Medi-Gap* | 94.1 (2.0) | 97.2 (0.6) | 97.2 (0.6) | 94.6 (1.2) | N/A | 65.4 (3.7) | 60.3 (3.5) | 53.6 (4.1)
Private | 92.2 (1.2) | 93.4 (0.9) | 91.8 (1.2) | 90.9 (1.6) | N/A | 61.9 (2.6) | 57.8 (2.6) | 49.8 (4.2)
Other^†^ | 96.2 (2.4) | 97.1 (2.4) | 93.1 (3.1) | 91.8 (2.6) | N/A | 70.0 (5.2) | 59.6 (6.6) | 59.2 (4.9)

All data are self-reported. Estimates are age-standardized to the NHANES 2017–2020 Q1 population with diabetes, using age groups 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and LDL cholesterol are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein; N/A, not applicable, data are not available in these survey periods.

* Medi-Gap was not included in the NHANES 1999–2004.

† Other insurance includes a state-sponsored plan or other government plan.

‡ A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

§ Self-report of a cholesterol test in the past 1–2 years

ǁ Foot exam is defined as a foot examination conducted by a health professional within the past 12 months, assessing the frequency of checks for sores or irritations. Self-reported.

¶ Physical activity standards are defined as ≥150 minutes of moderate or ≥75 minutes of vigorous leisure-time or work-related physical activity per week; physical activity is self-reported.

# Self-report of trying to lose weight in past year

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 1999–March 2020

TABLE 16.

Age-Standardized Trends in Vaccinations Among Adults Age ≥20 Years With Diagnosed Diabetes, by Insurance Status, U.S., 2000–2020

INSURANCE STATUS | PERCENT (STANDARD ERROR)
INSURANCE STATUS | Annual Influenza* | | | | | Pneumococcal, Ever^†^
INSURANCE STATUS | 2000 | 2005 | 2010 | 2015 | 2020 | 2000 | 2005 | 2010 | 2015 | 2020
No insurance | 50.8 (6.8) | 34.0 (10.9)^1^ | 41.7 (10.7) | 17.3 (4.0) | 33.8 (8.8) | 23.7 (8.6) | 23.2 (8.7) | 13.5 (1.8) | 13.1 (2.7) | 37.1 (9.2)
Any insurance | 55.4 (1.2) | 51.8 (1.2) | 60.4 (1.2) | 63.7 (1.1) | 64.8 (1.1) | 43.9 (1.2) | 48.2 (1.2) | 53.4 (1.1) | 54.7 (1.2) | 54.5 (1.1)
Medicaid | 49.9 (3.6) | 49.2 (3.0) | 55.5 (2.9) | 57.0 (2.4) | 59.2 (3.3) | 36.8 (3.1) | 44.0 (3.1) | 48.6 (2.9) | 48.9 (2.5) | 47.7 (3.0)
Medicare/Medi-Gap | 63.8 (2.4) | 58.9 (2.6) | 59.4 (2.4) | 67.6 (1.9) | 68.2 (2.3) | 56.3 (2.4) | 57.4 (2.7) | 58.9 (2.3) | 63.8 (2.3) | 64.0 (2.5)
Private | 57.1 (1.5) | 52.8 (1.4) | 63.6 (1.5) | 65.0 (1.4) | 66.8 (1.4) | 44.7 (1.5) | 51.1 (1.5) | 54.8 (1.5) | 55.8 (1.5) | 54.8 (1.3)
Other^‡^ | 54.0 (1.2) | 62.7 (3.8) | 65.7 (3.6) | 73.1 (2.9) | 69.1 (3.7) | 42.7 (1.2) | 65.9 (4.0) | 67.0 (3.4) | 62.6 (4.0) | 63.1 (3.6)

All data are self-reported. Estimates are age-standardized to the NHIS 2020 population with diabetes, using age groups 20–44, 45–64, and ≥65 years.

* Received a flu shot in the past 12 months.

† Ever received a pneumococcal vaccine.

‡ Other insurance includes a state-sponsored plan or other government plan.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Surveys (NHIS) 2000–2020

## Appendices

APPENDIX TABLE A1.

Raw Estimates of Trends in Risk Factor Control and Adherence to Preventive Measures Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 1999–March 2020

RISK FACTOR OR PRACTICE | PERCENT (STANDARD ERROR)
RISK FACTOR OR PRACTICE | 1999–2004 | 2005–2010 | 2011–2016 | 2017–2020
Risk Factors
A1C (%)
>9.0 | 16.0 (1.6) | 12.9 (1.0) | 15.0 (1.1) | 13.0 (1.3)
<8.0 | 70.2 (1.8) | 77.7 (1.4) | 71.6 (1.5) | 75.6 (2.3)
<7.0 | 48.9 (2.3) | 53.8 (1.9) | 50.8 (1.6) | 52.6 (3.1)
Blood pressure (mmHg)
<130/80 | 42.1 (2.2) | 50.2 (1.6) | 49.9 (1.4) | 47.6 (2.6)
<140/90 | 66.9 (1.6) | 70.9 (1.4) | 73.8 (1.4) | 71.3 (2.8)
LDL cholesterol
<100 mg/dL no ASCVD | 29.0 (2.9) | 39.0 (2.2) | 40.0 (2.7) | 46.4 (4.3)
< 70 mg/dL with ASCVD | 2.5 (0.8) | 6.8 (0.9) | 6.5 (0.9) | 9.1 (1.9)
<100 mg/dL without ASCVD or <70 mg/dL with ASCVD | 32.8 (2.7) | 46.7 (2.2) | 47.5 (2.6) | 56.0 (3.6)
Smoking status*
Never smoker | 47.0 (1.8) | 50.3 (1.3) | 49.1 (1.2) | 49.4 (2.7)
Former smoker | 33.1 (1.4) | 33.3 (1.1) | 35.5 (1.2) | 36.1 (2.9)
Current smoker | 19.9 (1.3) | 16.5 (1.0) | 15.4 (1.0) | 14.6 (1.3)
Composite measure achievement of A1C, blood pressure, LDL cholesterol, smoking status^†^ | 14.2 (2.2) | 24.1 (1.8) | 21.2 (2.2) | 25.0 (4.1)
Preventive Measures
Screenings
Lipid testing^‡^ | 86.1 (1.2) | 90.4 (0.7) | 90.5 (0.8) | 88.9 (1.1)
Routine examinations
Eye exam | N/A | 77.4 (1.2) | 79.6 (1.3) | 83.0 (1.2)
Dental exam | 29.2 (1.8) | N/A | 37.4 (2.1) | 40.5 (2.3)
Foot exam^§^ | N/A | 71.3 (1.3) | 71.6 (1.7) | 74.0 (1.8)
Health Behavior Measures
Self-glucose monitoring^‖^
More than once daily | N/A | 61.7 (2.8) | 61.4 (3.3) | 57.8 (3.1)
Physical activity^¶^
Met physical activity standards | N/A | 36.0 (1.5) | 39.4 (1.7) | 47.4 (2.5)
Insufficiently active | N/A | 14.5 (1.2) | 16.2 (1.3) | 15.9 (1.7)
Inactive | N/A | 49.5 (1.6) | 44.4 (1.8) | 36.7 (1.9)
Practicing weight control^#^ | 38.9 (2.1) | 41.5 (2.0) | 47.0 (1.7) | 46.1 (1.9)
Practicing diabetic diet | N/A | 62.7 (2.7) | 55.4 (2.8) | 56.7 (5.7)
Healthcare Utilization
Healthcare visit >1 time in past year | 91.1 (0.8) | 92.8 (0.7) | 89.8 (0.8) | 90.4 (1.0)
Seen diabetes specialist in past 2 years | N/A | 66.8 (2.0) | 62.4 (1.6) | 52.9 (2.6)

Diabetes status is self-reported. Conversion formulas for A1C and LDL cholesterol are available in the Conversions section. A1C, glycated hemoglobin; ASCVD, atherosclerotic cardiovascular disease, includes history of coronary heart disease, congestive heart failure, and stroke; LDL, low-density lipoprotein; N/A, not applicable, data are not available in these survey periods.

* Self-reported.

† A1C <8.0%, blood pressure <140/90 mmHg, LDL cholesterol <100 mg/dL without ASCVD or <70 mg/dL with ASCVD, and not current smoker

‡ Self-report of a cholesterol test in the past 1–2 years

§ Foot exam is defined as a foot examination conducted by a health professional within the past 12 months, assessing the frequency of checks for sores or irritations. Self-reported.

‖ Among those taking insulin

¶ Physical activity standards are defined as ≥150 minutes of moderate or ≥75 minutes of vigorous leisure-time or work-related physical activity per week; physical activity is self-reported.

# Self-report of trying to lose weight in past year

SOURCE: National Health and Nutrition Examination Surveys 1999–March 2020

APPENDIX TABLE A2.

Raw Estimates of Trends in Vaccinations Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., 2000–2020

VACCINATION | PERCENT (STANDARD ERROR)
VACCINATION | 2000 | 2005 | 2010 | 2015 | 2020
Annual influenza* | 51.6 (1.2) | 47.0 (1.1) | 57.5 (1.2) | 61.6 (1.1) | 63.4 (1.2)
Pneumococcal^†^ | 39.7 (1.2) | 43.3 (1.2) | 49.7 (1.1) | 52.7 (1.2) | 53.1 (1.1)

All data are self-reported.

* Received a flu shot in the past 12 months.

† Ever received a pneumococcal vaccine.

SOURCE: National Health Interview Surveys 2000–2020