# Psychosocial and Behavioral Health Among Youth and Adults With Diabetes

## Summary

Psychosocial and behavioral health concerns for people with diabetes have received increased attention over the past several years, and since the publication of the American Diabetes Association’s position statement calling for psychosocial care for people with diabetes, screening and treatment options have become more widespread. In this review, we use national datasets to describe the prevalence of psychosocial and behavioral health conditions in people with diabetes, which occur at higher rates than in the general population. These datasets were selected due to their large sizes, representativeness of the samples, and measurement of relevant constructs. Lifetime prevalence of depression in adults with diabetes is 25% (compared to 20% in the general adult population); anxiety diagnoses are reported by 20% of adults with diabetes (compared to 17.5% of adults without diabetes); eating disorders occur in 10% of females with diabetes, and disordered eating occurs in up to 38% of people with diabetes. Diabetes distress is also commonly experienced by people with diabetes; >30% of people with both type 1 and type 2 diabetes report clinically significant levels of diabetes distress.

In addition, we highlight the correlates and consequences of the psychosocial concerns most commonly experienced by people with diabetes, including depression, diabetes distress, anxiety, and disordered eating, as well as serious mental illnesses. Specifically, we note that females and young adults with diabetes are more likely to experience clinical diagnoses of depression, anxiety, and eating disorders than males or older adults with diabetes. Depression has been consistently associated with elevated glycemic outcomes in adults and youth, including higher glycated hemoglobin (A1C) levels and greater risk for diabetic ketoacidosis. In recent years, more studies have explored these topics in youth with diabetes and in representative populations. Finally, we identify measurement issues and review options for treatment and implications for clinical practice and future research.

## Introduction

This article highlights recent findings related to psychosocial and behavioral health concerns among people living with diabetes. The content herein is an update of the Diabetes in America, 3rd edition chapter Psychiatric and Psychosocial Issues Among Individuals Living with Diabetes (1) and includes a greater focus on diabetes distress and pediatric populations.

## Sources and Limitations of National Data on Psychosocial and Behavioral Health Among People With Diabetes

The Behavioral Risk Factor Surveillance System (BRFSS) is a large, state-based, telephone-based survey conducted annually to collect data on respondents’ health-related behaviors, chronic health conditions, and use of preventive services. This article uses data from the BRFSS 2022 and includes information on self-reported diagnosed diabetes, diabetes type, insulin use, and lifetime diagnosis of depression. Participants self-reported depression diagnoses, based on the question of “Has a health provider ever told you that you had a depressive disorder, including depression, major depression, dysthymia, or minor depression?” The BRFSS captures health data from a large, diverse population across the United States; however, most indicators related to diabetes and depression are self-reported, which is less reliable than using validated measurement tools, and the use of a telephone-based survey may not capture a representative sample.

The National Health and Nutrition Examination Survey (NHANES), conducted by the Centers for Disease Control and Prevention’s (CDC) National Center for Health Statistics, is a cross-sectional national probability sample that has been conducted periodically since 1971 and continuously since 1999. This article utilizes NHANES data collected from individuals for the period 2017–March 2020 to assess current estimates of depression among adults with diabetes. Participants self-reported diagnosed diabetes, based on the question “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” An advantage of the NHANES is that the survey includes a health exam in a mobile examination center where laboratory measures are collected. Thus, the NHANES has laboratory information on glycated hemoglobin (A1C) and fasting plasma glucose (FPG) levels to determine undiagnosed diabetes, prediabetes, and normal glucose. Participants reported depressive symptoms using the Patient Health Questionnaire (PHQ-9), a reliable and valid measure that scores the nine Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition Text Revision (DSM-5-TR) depression criteria for adults over the past 2 weeks on a scale from 0 (“not at all”) to 3 (“nearly every day”). The DSM-5-TR is the American Psychiatric Association’s medical reference book that defines the diagnostic criteria for mental health and brain-related conditions and disorders. The PHQ-9 components consist of somatic-affective criteria (i.e., sleep, fatigability, appetite, and psychomotor agitation) and cognitive-affective criteria (i.e., lack of interest, depressed mood, negative feelings, concentration problems, and suicidal intention). PHQ-9 scores range from 0 to 27 and can be used to categorize depressive symptoms from minimal to severe. A score of 0–4 is considered “minimal,” 5–9 is “mild,” 10–14 is “moderate,” 15–19 is “moderately severe,” and a score ≥20 is “severe.” Scores ≥10 are used to differentiate clinically significant depressive symptoms (2).

The National Health Interview Survey (NHIS), also conducted by the CDC’s National Center for Health Statistics, is a cross-sectional household interview survey that uses a complex sampling design and has been conducted continuously since 1957. In the NHIS 2022, participants were asked detailed questions about diabetes, depression, and anxiety. Diabetes is determined if participants answer “yes” to the following question: “(If female, other than during pregnancy) Have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Anxiety is determined if participants answer “yes” to the following question: “Ever been told by a doctor or other health professional that you had any type of anxiety disorder?” Participants self-reported depression, based on the question of “Have you ever been told by a doctor or other health professional that you had any type of depression?” Furthermore, a truncated Patient Health Questionnaire (PHQ-8, excluding the suicide intention item) is included in the NHIS. The PHQ-8 is scored similarly to the PHQ-9, with a score of ≥10 recommended as a cutoff point for screening depression. Although the questionnaire items in the NHIS are comprehensive, a limitation is that the data are self-reported.

## Depressive Disorders and Depressive Symptoms

### Overview and Definitions

Major depressive disorder (MDD), commonly called clinical depression, is the experience of depressed mood or a loss of interest or pleasure in daily activities, along with the presence of other specified symptoms related to sleep, eating, energy, concentration, or self-worth lasting for at least 2 weeks and interfering with social, occupational, or other important areas of functioning. Based on results from the 2021 National Survey on Drug Use and Health, the 12-month prevalence of MDD was 8.3% of U.S. adults and highest among U.S. adults age 18–25 years (18.6%) (3). The National Epidemiologic Survey on Alcohol and Related Conditions III (conducted in 2012–2013) indicated that lifetime prevalence of MDD was 20.6% (4), and lifetime prevalence was higher among women (26.1%) compared to men (14.7%). Among adolescents (age 12–17 years), 20.1% of the U.S. population had at least one major depressive episode in the past year; similar to adults, rates of MDD were higher among females (29.2%) compared to males (11.5%) (3).

### Measurement of Depression

While a diagnosis of MDD requires a clinical interview, depressive symptoms are typically assessed with self-report measures. The assessment of depression among people with diabetes may be complicated by overlapping symptoms. For example, hyper- or hypoglycemia may cause irritability, difficulty concentrating, and fatigue, all of which are key symptoms of MDD, and may therefore inflate the prevalence rates of depression. The literature suggests that the estimated incidence of depression depends on which measure of depressive symptoms is used. For example, older studies conducted in youth with diabetes used the Children’s Depression Inventory (CDI) (5), a measure of depressive symptoms for children between the ages of 7 and 17 years. Other studies used the Center for Epidemiologic Studies Depression (CES-D) measure (6), which was originally developed to measure depressive symptoms in adults but has been used in studies of youth age ≥12 years. More recent screening studies have used the PHQ, a tool designed to assess depression using the DSM-5-TR diagnostic criteria and validated for use in both adolescents and adults. Other studies have used structured clinical interviews to assess MDD, such as the Structured Clinical Interview for the DSM (SCID-5-RV) (7).

Rates of depressive symptoms in studies of youth with diabetes using the CDI and CES-D were much higher; they indicated that youth with type 1 diabetes were at two to three times the risk for clinically significant depressive symptoms as youth without diabetes (8). These measures do not map precisely onto DSM-5-TR symptoms the way that PHQ items do, and they may have been capturing some symptoms related to diabetes. For example, items such as “I felt people didn’t like me” and “I felt lonely, like I didn’t have any friends” do not reflect symptoms on the DSM-5-TR but may capture people feeling excluded due to diabetes. In contrast, prevalence of depression is lower among adolescents and young adults with type 1 diabetes (age 10–24 years) when using the PHQ screening tool. For example, in a study of four diabetes clinics that screened patients age 12–21 years, 7.6% screened positive with the PHQ-2 (using a cutoff score ≥3) and 6.7% screened positive with the PHQ-9 (using a cutoff score ≥5), indicating a least mild depressive symptoms (9). Another study of six pediatric diabetes clinics that used the PHQ-2 or PHQ-9 to screen for depression in youth age 12–24 years with type 1 diabetes (n=2,138) found that 10% reported clinically significant depressive symptoms (score ≥10). Given that the PHQ measure is based on diagnostic criteria from the DSM-5-TR, studies using this measure are likely to be capturing more accurate estimates of true levels of clinically significant depression. Finally, rates of depression are lower when studies have used psychiatric interview protocols, such as the SCID-5-RV (7).

### Prevalence and Course

#### Depression in Adults

Using BRFSS data from 2022, the prevalence of a lifetime diagnosis for depression was significantly higher for adults with diabetes compared to adults without diabetes (25.4% vs. 20.0%, p<0.001) (Table 1). The prevalence of a lifetime diagnosis for depression among adults with diabetes was highest in adults age 18–34 years (43.8%) and lowest in adults age ≥65 years (19.5%). Using survey data from the NHANES 2017–March 2020, the rates of clinically significant symptoms of depression based on a PHQ-9 score ≥10 were almost twice as high among adults who had been diagnosed with diabetes (12.9%) compared to those with normal glucose levels (7.6%; defined as A1C <5.7% [<39 mmol/mol] and FPG <100 mg/dL [<5.55 mmol/L]) (Table 2). Furthermore, across all diabetes diagnostic groups, those with non-zero PHQ-9 scores (meaning they endorsed at least one symptom) were most likely to report minimal depressive symptoms (or a score of 1–4), at relatively similar rates.

It is important to note that depression in people with diabetes may persist over time. A longitudinal study of adults with type 1 diabetes (n=2,744, mean age 42 years, 57% female) based on a national referral registry (T1D Exchange) found that 5% of participants reported persistently elevated depressive symptoms (PHQ-8 score ≥10) at baseline and follow-up 4 years later), 4% had resolved elevated depressive symptoms (clinically significant score at baseline, not at follow-up), 6% had new-onset elevated depressive symptoms (score in normal range at baseline, clinically significant score at follow-up), and 85% scored in the normal range at baseline and follow-up (10).

#### Depression in Youth

Across studies, youth with diabetes report higher rates of depressive symptoms than those without diabetes, but these rates vary widely due to the use of different measures of depression (see the Measurement of Depression section above). For example, in a registry study (Pediatric Diabetes Consortium of eight academic pediatric diabetes treatment centers) among youth with diabetes age 10–17 years screened for depression, clinically significant depressive symptoms were reported by 13% of youth with type 1 diabetes and 22% of youth with type 2 diabetes (11). A meta-analysis of six studies of youth with type 1 diabetes conducted between 2008 and 2015 found that the pooled prevalence of clinically significant symptoms of depression was 30% (8).

#### Suicidality

Based on data from the National Survey on Drug Use and Health 2022 (12), 5.2% of adults had serious thoughts of suicide, 1.5% made suicide plans, and 0.6% made suicide attempts in the past year. Suicide attempts are more likely among American Indian/Alaska Native or multiracial adults (1.5%) and more likely among men than women. In a systematic review and meta-analysis of suicidality among people with diabetes, 17 studies of suicidality indicated that the odds of suicidal ideation, attempted suicide, and completed suicide were significantly higher for people with diabetes compared to those without diabetes (odds ratios [OR] 1.89, 1.45, and 1.85, respectively) (13). Only one of these studies was conducted in the United States, however, and researchers found that among people with newly diagnosed type 2 diabetes, 9.7% had a history of a suicide attempt (14), which is higher than in the general population.

Based on national data from the Youth Risk Behavior Survey 2023, 20% of high school students in the general population had serious thoughts of suicide, 16% made a suicide plan, and 9% attempted suicide in the past year (15). These reports of suicidality have increased in the past decade; the percentage of female students with serious thoughts of suicide increased from 22% in 2013 to 27% in 2023, and the percentage of male students with serious thoughts of suicide increased from 12% in 2013 to 14% in 2023 (15). In a screening study of youth with type 1 diabetes age 10–24 years (n=550), 9% of the sample endorsed the PHQ-9 item assessing suicidality (responded affirmatively to “Thoughts that you would be better off dead, or thoughts of hurting yourself in some way?” in the past 2 weeks; PHQ-9 item #9) (16). A smaller study (n=133) from a single clinic found similar rates; 9.8% of adolescents and young adults (age 16–22 years) endorsed suicidal ideation on the PHQ-9, and 11.3% screened positive for current suicidal ideation on the psychologist-administered Columbia Suicide Severity Rating Scale (17). Similarly, in the screening study that included six pediatric diabetes clinics, 7% of youth (age 12–24 years) endorsed suicidal ideation on the PHQ-9 (18). Lower rates were observed in the Marker et al. screening study; of the youth who completed the PHQ-9, 3.1% endorsed suicidal ideation (9). It is important to note that two-thirds of adolescents and young adults who endorsed suicidality in clinic-wide screening were not receiving mental health treatment (18). Similarly, a screening study found that only 24% of youth who endorsed suicidality were seeing a therapist at the time of the risk assessment, and 39% reported ever seeing a therapist in the past (16).

### Factors Related to Prevalence of Depression in People With Diabetes

In the BRFSS 2022, the prevalence of lifetime diagnosis for depression was similar for adults with type 1 diabetes (29.9%) and type 2 diabetes using insulin (28.1%) but lower among adults with type 2 diabetes who were not using insulin (23.8%) (Table 1), possibly due to the burden or disease severity associated with insulin administration (19). Among adults with diabetes, insulin use was associated with a 26% increase in the odds of lifetime depression compared to non-insulin use (OR 1.26, 95% confidence interval [CI] 1.08–1.47) (Table 3). In contrast, youth with type 2 diabetes were significantly more likely to report moderate-severe symptoms (18.1%) than youth with type 1 diabetes (4.7%) in the SEARCH for Diabetes in Youth study (SEARCH) (20). Longitudinal analyses of SEARCH data found that depressive symptoms continued to be more common among youth with type 2 diabetes versus type 1 diabetes over time (21), possibly due to adverse social determinants of health.

#### Age

Similar to the general population, rates of lifetime diagnosis of depression are higher among younger adults (43.8% among adults age 18–34 years) than older adults with diabetes (Table 1). A meta-analysis of studies of depression among youth with diabetes (mean age 14.3±2 years) did not find a significant effect for age (22).

#### Sex

Similar to the general population, the prevalence of lifetime diagnosis for depression in adults with diabetes is higher among women (32.0%) than men (19.0%) in the BRFSS 2022 (Table 1). Similarly, in SEARCH, adolescent females were significantly more likely than males to report mild depressive symptoms (15.6% vs. 12.3%, respectively) and moderately severe/severe depressive symptoms (10.9% vs. 6.1%, respectively) (20). A meta-analysis of 66 studies of the prevalence of depressive symptoms in youth with type 1 diabetes and type 2 diabetes found that the pooled prevalence of clinically significant depressive symptoms in females (29.7%) was significantly higher than in males (19.7%) (20). In contrast, the screening data from six pediatric diabetes clinics did not identify a significant difference in depressive symptoms related to sex (18), and no significant association with sex was observed in the Pediatric Diabetes Consortium study (11).

#### Race and Ethnicity

In adults with diabetes, the lifetime prevalence of a depression diagnosis is somewhat higher among non-Hispanic White (27.6%) and non-Hispanic American Indian/Alaska Native (24.9%) people compared to non-Hispanic Black (21.9%) or Hispanic (22.9%) people (Table 1). In contrast, the study of depression screening across four pediatric diabetes clinics found that greater depressive symptoms were endorsed by adolescents and young adults from minoritized racial and ethnic groups compared to White youth (9). However, the screening data from six pediatric diabetes clinics did not find significant differences in depressive symptoms related to race or ethnicity (18).

### Association of Depression and Depressive Symptoms With Diabetes Treatment Outcomes

#### A1C

A meta-analysis of longitudinal studies of adults with type 1 diabetes or type 2 diabetes found that higher baseline A1C was associated with more depression over time, regardless of prevalent depression. Specifically, among five studies that assessed depression as an outcome, a one-point higher baseline A1C level was associated with 18% increased risk for depression at follow-up (23). This meta-analysis also included six studies that assessed A1C as an outcome, and higher baseline depressive symptoms were associated with higher A1C over time, suggesting bidirectional effects (23). In other words, it is possible that depressive symptoms can lead to higher A1C over time and that people experiencing higher A1C go on to develop greater depressive symptoms. Significant, positive associations between depressive symptoms and A1C have been observed consistently across studies in youth and adults with diabetes. For example, a longitudinal study of data from the T1D Exchange found that an increase in depressive symptoms was associated with an increase in A1C over 4 years among adults with type 1 diabetes (10). On the other hand, a study using NHANES 2017–2018 data for adults with either type 1 diabetes or type 2 diabetes (n=429) found that having an A1C >7% (>53 mmol/mol) was associated with greater likelihood of having at least mild depressive symptoms (PHQ-9 score ≥5); however, after adjusting for sex, race and ethnicity, socioeconomic status, body mass index, and sedentary lifestyle, this association was no longer significant (24).

The screening study of adolescents and young adults with type 1 diabetes across six pediatric diabetes clinics also found a significant association between PHQ-9 score and A1C (18). Similarly, the meta-analysis of youth with type 1 diabetes found a significant association between CDI scores and A1C in five studies (8). A study of adolescents found that elevated depressive symptoms were associated with higher A1C in those with type 1 diabetes but not those with type 2 diabetes (25). In a study of 12–19-year-olds, those with type 1 diabetes who had clinically significant depressive symptoms (PHQ-9 score ≥11) had higher A1C levels than those who did not have symptoms (PHQ-9 score <11) (10.5% vs. 9.5%, respectively), and the elevated symptoms group was more likely to have an A1C >14% (>130 mmol/mol) (26). These effects were moderated by sex; the association between clinically significant depressive symptoms and A1C was significant for females but not for males (26).

#### Diabetic Ketoacidosis

Depressive symptoms have been associated with increased risk for diabetic ketoacidosis (DKA) among people with diabetes. For example, in one study of adults with type 1 diabetes, participants with persistent elevated depressive symptoms and new-onset elevated depressive symptoms were more likely to report DKA resulting in hospitalization at follow-up than those in the resolved depressive symptoms or no depression groups (10). Additionally, a study of adults found that one of the most important factors for predicting hyperglycemic crises (DKA and hyperglycemic hyperosmolar state) was depression for both type 1 diabetes and type 2 diabetes (27). Similar findings have been observed in youth. Mulvaney et al. found higher depressive symptoms in youth with at least one DKA event in the prior year (18), and an analysis of T1D Exchange data found that adolescents age 12–18 years with type 1 diabetes who endorsed at least mild depressive symptoms (PHQ-9 score ≥5) had an 82% increased risk of DKA compared to those who did not endorse depressive symptoms (28).

### Causal and Explanatory Mechanisms for Depression and Depressive Symptoms in People With Diabetes

A review article on 25 years of research on depression and diabetes confirms that the relationship between depression and type 2 diabetes is bidirectional (29). In a meta-analysis that assessed longitudinal associations between these variables in adults, the risk of developing diabetic complications was higher among people with depression than the risk of people with diabetic complications developing depression (30).

Insufficient sleep has been associated with depressive symptoms in the general population and among youth with type 1 diabetes (31). In addition, given associations between extremely low A1C and depression, it may be that the burden of meeting glycemic targets increases risk for depression (24) or that more frequent hypoglycemia associated with low A1C causes disturbed sleep, thereby increasing risk for depression.

### Treatment and Intervention for Depression and Depressive Symptoms

Based on data from the National Survey on Drug Use and Health study from 2022, more than 60% of people diagnosed with MDD receive treatment (32). In adults with type 2 diabetes, interventions targeting the treatment of depression have demonstrated significant effects on both depression and glycemic outcomes. For example, a randomized, multistate, community-based depression treatment for adults with type 2 diabetes (Program ACTIVE II) compared cognitive behavioral treatment (CBT) for depression with a community-based exercise program or usual care (33). Researchers found that participants who received either intervention had significantly greater odds of achieving remission from depression than those in the usual care group (OR 5.0 for CBT and 6.8 for exercise), and participants who received both the CBT and exercise interventions exhibited significant improvements in A1C compared to usual care. The use of antidepressant medication (selective serotonin reuptake inhibitors [SSRIs]) to treat comorbid depression and diabetes may also be effective; a review of 18 randomized trials found significant effects of SSRIs on depressive symptoms and some positive effects on A1C (34).

In the general population, more than 40% of adolescents diagnosed with MDD receive treatment (32). Yet, screening studies indicate that most youth who report depressive symptoms are not receiving mental health treatment. For example, in the Pediatric Diabetes Consortium study, only 14% of youth with type 1 diabetes and 15% of youth with type 2 diabetes who reported severe depressive symptoms had a diagnosis of depression in their medical record, and the majority of those with a diagnosis had not received treatment in the previous year (11).

However, a study examining the effects of receiving counseling for depression found that A1C was not significantly different for adolescents one year later whether or not they had attended counseling (25). An intervention aimed at reducing risk for depression in adolescents using the Penn Resilience Program for T1D (STePS Program) found no differences in depression or A1C between adolescents who received the intervention and those who received a diabetes education program, but the adolescents in the intervention group reported significantly lower levels of diabetes distress after 12 months (35). Treating sleep disturbances/insufficient sleep with approaches such as CBT for insomnia may be a way to improve mental health in youth with type 1 diabetes (31).

## Diabetes Distress

### Overview and Definitions

Diabetes distress, or the emotional burden of managing and living with diabetes, was included in the American Diabetes Association’s position statement calling for psychosocial care for people with diabetes (36). Diabetes distress includes worry and stress related to various aspects of diabetes management, including the emotional burden, physician-related stress, regimen-related distress, and diabetes-related interpersonal distress (37). It has been evaluated in people living with type 1 diabetes and type 2 diabetes, among teens (38) and children with diabetes (39), and in caregivers of children with diabetes (40), as well as family members of adults with diabetes (41). Diabetes distress is distinct from depression and general well-being (42); as noted in an earlier review on the distinction between depression/depressive symptoms and diabetes distress, depression is a symptom-based disorder that does not account for the context of individuals’ lives, whereas diabetes distress is an emotional response to a clear stressor (43).

### Measurement of Diabetes Distress

The most commonly used measures of diabetes distress are the Diabetes Distress Scale (DDS) and the Problem Areas in Diabetes (PAID), which include subscales related to Emotional Burden, Physician-related Distress, Regimen-related Distress, and Interpersonal Distress. Shorter forms are available for screening, including the DDS-2 (a two-item screener) (44) and the PAID-5 (a five-item screener), which demonstrate satisfactory sensitivity and specificity (45). These measures have been adapted to assess diabetes distress in youth of different ages, including the PAID-Teen (PAID-T) and the PAID for children age 8–12 years (PAID-C) (38,39). In addition, measures have been developed to assess diabetes distress among caregivers of children with diabetes (DDS–Parent version; P-PAID-T Parent scale, P-PAID-C) (38,39), as well as among family members of adults with diabetes (PAID-FM) (41). However, the researchers who developed these measures recently recommended that the measurement of diabetes distress include a two-part measure: a core measure that characterizes the emotional burden and source scales that identify the most salient contributors to individuals’ diabetes distress (46).

### Prevalence and Course

A meta-analysis of 55 studies of diabetes distress in adults (n=36,998) found that ~36% of adults with type 2 diabetes reported clinically significant distress (47). A systematic review of 16 studies that assessed diabetes distress in youth with type 1 diabetes found that about 30% of adolescents reported clinically significant levels of diabetes distress, using cutoff scores on validated measures (48). These findings highlight how common diabetes distress is among people with diabetes.

### Factors Related to Prevalence of Diabetes Distress

#### Age

Diabetes distress was not significantly associated with age in adults with type 2 diabetes (47) or adults with type 1 diabetes, but an earlier study found that younger adults with type 1 diabetes (age <41 years) reported higher diabetes distress than older adults with type 1 diabetes (49,50). A systematic review of diabetes distress in adolescents (age 12–18 years) found inconsistent results for associations between age and diabetes distress. Six studies found no significant association, three studies found higher levels of diabetes distress in persons of older age, and one study found lower levels of (dietary-related) diabetes distress at older ages (48).

#### Sex

In the meta-analysis of diabetes distress among adults with type 2 diabetes, women reported significantly higher levels of diabetes distress than men (Cohen’s d effect size = -0.13, p=0.011) (47). In a systematic review of diabetes distress in adolescents, three studies found that females’ diabetes distress scores were higher than males’ scores, but eight studies did not find a significant differences in diabetes distress related to sex (48).

#### Race and Ethnicity

In a 2024 study, diabetes distress levels among urban Black adolescents with type 1 diabetes were higher than found in other studies of adolescents with type 1 diabetes (58% reported elevated diabetes distress compared to ~30% in other studies) (51). A study of adults with type 2 diabetes found that non-Hispanic White participants reported greater regimen-related diabetes distress and physician-related diabetes distress than Black participants over 6 months, but no differences were observed by race in diabetes distress related to emotional burden or interpersonal distress (52). In another study comparing Black/African American adults with White adults with type 2 diabetes (all age ≥65 years), Black/African American participants reported higher levels of diabetes distress compared with White participants, after controlling for demographics, social support, and cognition (53). Future studies may shed light on racial and ethnic differences in diabetes distress.

#### Diabetes Duration

Most studies in adolescents with type 1 diabetes (five of six studies) found no significant association between diabetes distress and diabetes duration (48). In the one study, adolescents (age 12–18 years) with longer diabetes duration reported lower diabetes distress (r = -0.19, p<0.01) (54).

### Association of Diabetes Distress With Diabetes Treatment Outcomes

Diabetes distress is consistently associated with lower levels of diabetes self-management behaviors and higher A1C levels in adults (55). Diabetes distress has also been found to be positively associated with A1C among adolescents. In a systematic review, 8 of 12 studies of adolescents with type 1 diabetes or type 2 diabetes found a significant positive association between diabetes distress and A1C (r = 0.13–0.30) (48). Similarly, a more recent study found that diabetes distress was more strongly associated with higher A1C levels than depressive symptoms in adolescents (age 13–17) with type 1 diabetes (56). A1C was significantly associated with diabetes distress among urban Black adolescents with type 1 diabetes (r = 0.37 in preadolescents, 0.39 in adolescents) (51). Furthermore, adolescents with type 1 diabetes (age 13–17 years) and young adults with early-onset type 2 diabetes (diagnosed before age 18 years) who report clinically significant rates of diabetes distress have significantly higher A1C levels than those who report low diabetes distress (57,58).

### Treatment and Intervention for Diabetes Distress

A meta-analysis of psychosocial interventions to reduce diabetes distress in adults with type 2 diabetes that included 18 studies found a significant reduction in diabetes distress at 3 months (standardized mean difference [SMD] -0.18, p=0.02), 6 months (SMD -0.20, p=0.006), and 12 months (SMD -0.21, p=0.009), but the authors caution that the quality of the evidence was very low-moderate due to serious risk of bias (59). No significant effect of the interventions was found on A1C at any follow-up time point. More recently, Hessler et al. conducted a large randomized controlled trial (RCT) in adults with type 1 diabetes comparing the effects of a diabetes education program, an emotion-focused intervention for diabetes distress, or an integration of the two programs. They found that participants in all three groups reported significant reductions in diabetes distress (d = 0.58–1.14), with larger effects in those who received the emotion-focused intervention or integrated intervention (60).

In adolescents, few interventions to reduce diabetes distress have been tested and reported. Only one recent RCT in adolescents with type 1 diabetes (n=172) of a resilience-building intervention found a significant reduction in diabetes distress over 12 months compared to usual care (61).

## Anxiety Disorders, Symptoms of Anxiety, Fear of Hypoglycemia, and Fear of Self-Injection

### Overview and Definitions

Anxiety disorders, broadly defined by the DSM-5-TR as anxiety or worry that interferes with functioning or causes significant distress, can include a constellation of symptoms, including excessive fear or worry, intrusive thoughts or concerns, hyperarousal, and impairment, including avoidance of feared situations and distress (62). Anxiety disorders are among the most common psychiatric conditions in the Western world (63). In the United States, the prevalence was as high as 19.1% in 2001–2003, with a 31.1% lifetime prevalence (64). Impairment in daily functioning from anxiety disorders is substantial. Among individuals with anxiety disorders, 22.8% report serious impairment, 33.7% report moderate impairment, and 43.5% report mild impairment (64). There are sex differences in the prevalence of anxiety disorders. Women are twice as likely to be affected by anxiety disorders as men (65), with prevalence rates of 23.4% for women and 14.3% for men (64). Younger individuals (age <35 years) are more likely to have anxiety disorders than older individuals (65). Among adolescents, there is a 31.9% lifetime prevalence of anxiety disorders, with 8.3% reporting severe impairment. Similar to adults, there are sex differences in adolescents, with more females (38.0%) than males (26.1%) diagnosed with anxiety disorders (64).

There are several specific anxiety disorders each with unique features, including generalized anxiety disorder (66), panic disorder (67), and specific phobias, which are characterized by intense fear of a specific thing that poses little or no actual danger (68). Fears or worries of hypoglycemia and insulin self-injections are conceptualized as specific phobias and discussed below. Throughout this section the term “self-injection” will be used inclusively to describe injection via syringe, pen, pump automatic inserters, and inserting a continuous glucose monitoring (CGM) device.

### Measurement of Anxiety

As discussed, measurement of anxiety, like the measurement of depression, is complicated by the overlap among physical symptoms common to both diabetes and anxiety. Commonly used measures to assess generalized anxiety in people with diabetes include the Generalized Anxiety Disorder Assessment (GAD-7) (69) and the Depression, Anxiety, and Stress Scale (DASS) (70). Specific to fear of hypoglycemia (FoH), the Hypoglycemic Fear Survey is frequently used (71). Additionally, a certain amount of worry and anxiety facilitates diabetes self-management and may be beneficial for adults with diabetes. Hypoglycemia and anxiety symptoms have commonalities, such as dizziness, shakiness, lack of coordination, and racing heart. With the onset and high uptake of CGM devices, it was hypothesized that better in-the-moment knowledge of glycemia would improve people’s ability to self-assess anxiety symptoms. However, in a large sample of adults with type 1 diabetes, despite high use of CGM (91.7%) and automated insulin delivery (50.8%), approximately 20% reported severe hypoglycemic events and 30.7% experienced impaired awareness of hypoglycemia, suggesting that these new technologies have not completely overcome issues of self-awareness of symptoms (72). Furthermore, constant awareness of glucose levels may contribute to anxiety and diabetes distress.

### Prevalence and Course

#### Anxiety in Adults

The exact prevalence of anxiety disorders among individuals with diabetes is difficult to estimate; however, it is well documented that the prevalence of anxiety disorders is higher among adults with diabetes than in the general population (65). A meta-analysis found that diabetes is positively associated with anxiety symptoms (OR 1.48, 95% CI 1.27–1.74) (73). Specific to type 2 diabetes, diabetes and anxiety are positively associated (OR 1.67, 95% CI 1.23–2.25, p=0.001) (73). Likewise, adults with diabetes have higher prevalence of any anxiety disorder and specific phobia (74). Specific to adults with type 1 diabetes, one review found that the prevalence of anxiety was 25% (75).

Based on NHIS 2022 data, the prevalence of self-reported anxiety diagnoses for adults with diabetes was 20.4%, significantly higher than for adults without diabetes (17.5%; Table 4). Both men and women with diabetes were significantly more likely to have anxiety diagnoses than adults without diabetes (15.6% vs 12.3%; 25.3% vs 22.3%, respectively). Individuals with diabetes identifying as non-Hispanic White, non-Hispanic Black, or Hispanic were more likely to have anxiety diagnoses than their counterparts without diabetes. Finally, adults with diabetes and anxiety diagnoses were less likely to endorse co-occurring depression than adults without diabetes. Of note, the results from the NHIS should be interpreted with caution, as measurement of anxiety diagnoses is self-reported with a single item.

Among individuals with diabetes, there are two well-identified specific phobias: fears or worries about hypoglycemia and insulin self-injection. The specific phobia of FoH is characterized by fears that are persistent, recurrent, or objectively inappropriate given the risk of hypoglycemia (76,77). The prevalence of FoH is as high as 30% in adults with type 1 diabetes (78) and as high as 26% in adults with type 2 diabetes (79). FoH may result in people maintaining higher glucose levels to prevent lows, which increases risk of long-term complications (77). FoH can also impact parents, caregivers, and close relationships of children with type 1 diabetes (80). The second specific phobia relevant to diabetes is a specific phobia of insulin self-injections. The prevalence of the specific phobia of insulin self-injection is 0.2%–1.3% and that of self-testing is 0.6%–0.8% among adults with insulin-treated diabetes (58.0% of the sample had type 1 diabetes) (81). Fear of insulin or fear of insulin self-injection is associated with below-target glycemic management, suboptimal well-being, and increased risk of mortality for individuals with diabetes (82,83).

#### Anxiety in Youth

One review of the prevalence of anxiety disorders in youth with type 1 diabetes found the prevalence of state anxiety, a temporary emotional response to a situation, was 13.4%, and the prevalence of trait anxiety, a personality trait associated with experiencing anxiety in stressful situations, was 17% (8). In another study, 21.3% of youth with type 1 diabetes were positive for an anxiety disorder cross-sectionally (84), and in a longitudinal sample of youth with type 1 diabetes, 19.6% developed an anxiety disorder over 9 years following type 1 diabetes diagnosis (85). Another meta-analysis found the global prevalence of anxiety among youth with type 1 diabetes was 17.7% (95% CI 15.2%–20.1%), with higher estimates specific to the Americas (23.8%, 95% CI 7.3%–40.3%) (22). Among adolescents with type 1 diabetes, fear of self-injection is independently associated with older age, multiple daily insulin injections, and fewer finger pricks (86), and fear of self-testing is independently associated with a fewer number of finger pricks (86). In youth, FoH is associated with higher frequency of severe and other hypoglycemic episodes and higher trait anxiety (87).

### Factors Related to Prevalence of Anxiety in People With Diabetes

Limited data exist on the identification of risk factors for anxiety in adults with diabetes. Mirroring findings in the population at large, women with diabetes are two times as likely to have anxiety as men with diabetes (55.3% vs. 32.9%) (88). Additionally, one study found neuroticism, a common personality trait defined as a tendency towards negative feelings, was associated with anxiety and diabetes self-management in sample of women with diabetes (89).

As in the general population, there are sex-related differences in anxiety among youth with type 1 diabetes. In a study of 11–14-year-olds with and without type 1 diabetes, higher anxiety scores were found in children with diabetes than those without diabetes (8). Lastly, females have higher anxiety than males among youth with type 1 diabetes (85).

### Association of Anxiety With Diabetes Treatment Outcomes

Research on the association between anxiety and outcomes for people with diabetes has yielded mixed results. Some studies have not found significant associations between anxiety and A1C (90,91), while others have found positive associations (92). A meta-analysis of 11 studies did not find associations between anxiety and glycemic management overall; however, when restricting to studies that used diagnostic interviews, there was a significant positive association (effect size = 0.25, p=0.003) (93). Among Black/African American adults (n=42), anxiety was positively associated with A1C but not with self-management behaviors (92). Finally, a small study (n=24) of adults with diabetes with fear of self-injection or self-testing found higher diabetes distress and worse treatment adherence (81).

In youth with type 1 diabetes, higher symptoms of anxiety are associated with higher A1C (8). Specifically, one study found that state anxiety (current symptoms) was associated with higher A1C, lower blood glucose monitoring rates, and poorer quality of life in youth with type 1 diabetes (85), whereas trait anxiety (stable symptoms) was associated with higher FoH and more episodes of hypoglycemia in youth with type 1 diabetes (85).

### Causal and Explanatory Mechanisms for Anxiety in People With Diabetes

The well-documented association between anxiety and diabetes begs the question of causality. Two studies sought to understand the directionality of the relationship between anxiety and diabetes using longitudinal methods. A systematic review and meta-analysis found no association between baseline anxiety and incident diabetes; however, only two studies were included, and more research may be useful to establish causality between diabetes and subsequent anxiety (94). Second, a longitudinal study of diverse adults found that a positive anxiety screen is a risk factor for developing diabetes, independent of traditional diabetes risk factors and positive depression screen (95).

Several possible mechanisms could explain the relationship between diabetes and anxiety. Although biobehavioral research in this area is sparse, plausible mechanisms linking anxiety and diabetes include reactions to the stress associated with self-management of diabetes and the underlying biologic changes that may be associated with both anxiety and glycemic management. Specifically, adults with diabetes may experience short-term stress related to self-care and/or long-term, chronic stress related to living with a chronic condition. Over time, one or both of these sources of stress could develop into anxiety symptoms and meet diagnostic criteria for an anxiety disorder. Chronic stress may negatively impact health behaviors, including food choices, physical activity, and medication adherence, all of which in turn could increase the risk for or severity of diabetes (96). The chronic psychological stress associated with managing a chronic illness may result in hypothalamic-pituitary-adrenal activation, which increases cortisol (97). Likewise, activation of the autonomic nervous system increases epinephrine and norepinephrine, which can contribute to insulin resistance and higher A1C (97). Together, these pathways could explain the relationship between stress and anxiety and type 2 diabetes (97). Though it is plausible a similar pathway is at work in type 1 diabetes, research has not yet been done to describe such associations. There is also potential for a negative feedback loop whereby anxiety impedes self-care, which leads to below-target glycemic management and possible complications, which in turn leads to greater levels of anxiety.

One study found that rats exposed to a high-fat diet demonstrated anxiety-related behaviors, as well as disrupted insulin signaling, suggesting a possible common risk factor between type 2 diabetes and anxiety (98). Additionally, anxiety disorders often co-occur with tobacco and other substance use (99), highlighting a potential pathway between anxiety and suboptimal diabetes outcomes. Finally, one study found trait anxiety did not predict incidence of type 2 diabetes in a multiethnic sample; however, trait anger did (100). There is substantial work to be done to understand the directionality and causal nature of these relationships.

### Treatment and Intervention for Anxiety

Stress management interventions for adults with type 2 diabetes reduce symptoms of anxiety but may not improve diabetes outcomes. One study found improved glycemic management over a 1-year follow-up of a group-based stress management intervention (101), while an RCT of a stress management intervention for U.S.-based Latino people found improvements in stress but no difference in glycemic management at 3 months (102). Mindfulness interventions have also been tested to manage stress with diabetes. A systematic review of mindfulness-based interventions did not find intervention effects on glycemic management in larger samples, though smaller, tailored studies did find improvements in glycemic management (103). All studies that assessed anxiety found reductions in anxiety as a result of the mindfulness interventions (103). Similar to mindfulness practices, evidence is emerging that yoga may improve glycemic management and body composition; however, high-quality evidence is needed for conclusive statements (104). The model of collaborative care, which has support for anxiety and diabetes, has been recommended, especially within primary care settings (105). Specific to FoH and fear of self-injection, an RCT of using CGM versus self-monitoring did not find that CGM improved hypoglycemic fear in adults with type 1 diabetes (106); however, CBT may be an effective treatment for fear of self-injection (107). Additionally, psychoeducation interventions have some support for treating FoH in adults (76), while an RCT found support for CBT to reduce FoH in youth (108).

Specific to youth with diabetes, a few quasi-experimental studies have been conducted to treat anxiety. A pre-post study of a pediatric summer camp for youth with type 1 diabetes found decreased anxiety levels (109), and in a small (n=6) sample of youth with type 1 diabetes, CBT improved anxiety symptoms in four of the youths (110). Lastly, similar to adults, an RCT of CGM versus usual care did not decrease diabetes-related anxiety in youth with type 1 diabetes (111). It is also important to note that many individuals experience comorbid symptoms of anxiety and depression (e.g., (112)), and therefore, treatment options targeting emotional distress more broadly may be beneficial.

## Eating Disorders, Unhealthy Eating Behavior and Attitudes, and Insulin Omission for Weight Loss

### Overview and Definitions

Eating disorders refer to clinical diagnoses of unhealthy behavior around eating as established by the DSM-5-TR (62). The most common eating disorders are anorexia nervosa, bulimia nervosa, and binge eating disorder (BED). Anorexia nervosa is characterized by an obsessive drive for thinness, distortion of body image, and often a fear of gaining weight. This typically results in severe restriction of food intake and/or increase in physical activity, which can lead to emaciation. Roughly 0.6% of the U.S. population will have anorexia nervosa in their lifetimes, with prevalence rates three times higher for females compared to males (113). Bulimia nervosa is characterized by body dissatisfaction, periods of “binging” (eating an excessive amount of calories in a short period of time), feeling loss of control during these binge episodes, and compensating for these calories afterwards by purging (e.g., vomiting), over-exercising, and/or fasting. Prevalence of bulimia nervosa in the United States is 0.3%, with rates five times higher in females compared to males (113). BED is characterized by binge eating episodes that do not include compensation after binging. Typically, BED includes a feeling of being out of control while binging and feelings of guilt or shame after binging. Roughly 1.2% of the U.S. population is diagnosed with BED, and females have two times the prevalence of males (113).

While these are the most common types of eating disorders, the DSM-5-TR includes two other eating disorder diagnoses. Other specified feeding or eating disorders (OSFED) include eating behaviors causing significant distress but not meeting the criteria of the other eating disorders. Insulin restriction for weight control falls under this category, as it is a behavior in which a person with type 1 diabetes takes little or no insulin to lose weight or keep from gaining weight. Because this is a kind of “catch all” diagnosis for those who do not fit into other categories, it has the highest prevalence, affecting 3.8% of women and 1.6% of men in the United States (114).

For an eating disorder to be diagnosed, a clinician must conduct a clinical interview with the person being assessed. Eating behaviors and patterns that are atypical and unhealthy but do not meet the clinical threshold for an eating disorder are typically referred to as “disordered eating behavior.”

### Measurement of Eating Disorders and Disordered Eating

Measuring disordered eating in people with diabetes using traditional measures may result in inflated rates of disordered eating. The recommended self-management of diabetes requires a focus on nutrition, as carbohydrates directly affect blood glucose levels, and other nutritional components, such as protein and fat, can affect insulin sensitivity. Appropriate diabetes management behavior, therefore, may be incorrectly flagged as disordered eating when using traditional measures. For example, a common measure of disordered eating is the Eating Attitudes Test – 26 (EAT-26) (115), which has the items “I particularly avoid food with a high carbohydrate content (i.e., bread, rice, potatoes, etc.),” “I avoid foods with sugar in them,” and “I eat diet foods.” People with diabetes may endorse these items due to the impact high carbohydrate foods have on blood glucose, rather than because they have an eating disorder. In addition, measures that ask about eating when not hungry may incorrectly flag appropriate responses to low blood glucose in people with diabetes (116).

Currently, only one measure has been created specifically to measure disordered eating behaviors in diabetes, the Diabetes Eating Problem Survey–Revised (DEPS-R) (117). This scale asks questions about disordered eating behavior, as well as eating in relation to diabetes management, and is the only disordered eating scale to have questions specifically related to insulin restriction to lose weight. This scale is currently the most commonly used measure of disordered eating in people with diabetes, as other measures do not take into account how diabetes management impacts behaviors around food. It is also important to consider that some people may restrict or ration insulin due to other factors, such as cost (118).

Research using different measures highlights the sensitivity required to accurately assess disordered eating in people with diabetes. A meta-analysis of studies that assessed disordered eating prevalence in young adults with type 1 diabetes compared with their peers found that generic measures of disordered eating inflated prevalence estimates compared to diabetes-specific measures, and the use of generic measures resulted in exaggerated differences between people with diabetes and their peers (119).

### Prevalence and Course

For adults with type 2 diabetes, eating disorders are observed in 1.4%–25% (120), with the most common type of eating disorder being BED (121). One study found that compared to people without diabetes, those with type 2 diabetes had significantly higher rates of BED, but not bulimia (122). When examining insulin restriction for weight control in people with type 1 diabetes, prevalence rates have varied widely, from <1% to 61.7% (123). Insulin restriction has rarely been examined in type 2 diabetes populations. However, one study examined disordered eating behaviors in a sample of both type 1 diabetes and type 2 diabetes studies and found that only participants with type 1 diabetes engaged in insulin restriction (123).

Most of the literature on disordered eating behaviors in diabetes has focused on adolescents and young adults with type 1 diabetes and often only on females. In these studies, the prevalence of disordered eating has ranged from 7.8% to 68.9% when using any measure, but these rates drop to 7.8%–42% when using diabetes-specific measures of disordered eating behaviors (124). The SEARCH study reported 21.2% of youth with type 1 diabetes and 50.3% of youth with type 2 diabetes prescribed insulin engaged in disordered eating behaviors (125). A meta-analysis showed that for adolescent females with type 1 diabetes, rates of anorexia nervosa were not different compared to controls without diabetes, but rates of bulimia were higher for the diabetes group (126). For adults with type 1 diabetes, when using diabetes-specific measures of disordered eating, a 2020 review showed that 19%–35% had disordered eating behaviors (124). Similarly, a 2024 meta-analysis found that studies of disordered eating behaviors in those with both type 1 diabetes and type 2 diabetes using the DEPS-R measure resulted in a pooled prevalence rate of 27% (127).

### Factors Related to Prevalence of Disordered Eating in People With Diabetes

#### Age

A study of adolescents and young adults with either type 1 diabetes or type 2 diabetes found that for both types of diabetes, the prevalence of disordered eating was highest at age 15–19 years (125).

#### Sex

Females are more likely to engage in disordered eating than males, although males with diabetes do engage in disordered eating more than their counterparts without diabetes (128). A review showed that females with type 1 diabetes had more than double the rates of eating disorders compared to those without diabetes, and that females with type 1 diabetes had more than double the prevalence of disordered eating behaviors compared to males with type 1 diabetes (Table 5) (129).

#### Psychosocial Factors and Diabetes Technology

Disordered eating behaviors have been associated with an avoidant coping style, diabetes-specific distress, diabetes family conflict, higher anxiety, and depressive symptoms in people with both type 1 diabetes and type 2 diabetes (128).

Recent attention has been paid to the role of diabetes technology in disordered eating behaviors. A systematic review examined how insulin pumps and CGM are associated with disordered eating. The review found mixed results for insulin pumps, with some studies indicating that those who use insulin pumps have less disordered eating than those who use multiple daily injections, while others found no significant differences (130). The review did not include studies that examined the association between CGM use and disordered eating but did suggest that CGM could be used to assess disordered eating behaviors.

### Association of Disordered Eating With Diabetes Treatment Outcomes

Eating behaviors influence diabetes management, and disordered eating can impact glycemic control. Disordered eating behaviors generally have been associated with higher A1C in type 1 diabetes populations (131), and binge eating is particularly harmful for diabetes management, as eating large amounts of carbohydrates in a short period of time even with insulin increases blood glucose levels (132). A study of people with type 2 diabetes and eating disorders that included BED found that disordered eating behaviors were associated with greater variability in blood glucose levels and that those who had an eating disorder had higher blood glucose variability than those without eating disorders (133). However, while binging affects blood glucose variability and levels, studies have not found direct impacts on A1C (121).

Disordered eating behaviors are also associated with other negative health outcomes for people with diabetes. In one study of adolescents and young adults with type 1 diabetes, researchers found those with eating disorders had a threefold higher risk of DKA and a nearly sixfold higher risk of death compared to their peers without eating disorders (134). Indeed, disordered eating behaviors that include limiting or constraining foods can increase the risk of hypoglycemia, which if left untreated can result in severe complications or death (135,136). In addition, for young people with either type 1 diabetes or type 2 diabetes, disordered eating behaviors are associated with lower insulin sensitivity (125).

While disordered eating generally is associated with poor diabetes health outcomes, insulin restriction specifically is extremely dangerous for those with diabetes. In both type 1 diabetes and type 2 diabetes, insulin restriction is associated with higher A1C and has also been linked with other complications, such as neuropathy and retinopathy (137). Additionally, a longitudinal study of females with type 1 diabetes found that those who engaged in insulin restriction at baseline had a threefold increased risk of death 11 years later (138).

### Causal and Explanatory Mechanisms for Disordered Eating in People With Diabetes

Various explanations have been proposed to explain the associations between eating disorders and diabetes outcomes. Specifically, family functioning (e.g., lower levels of family cohesion and family support) has been associated with disordered eating in females with and without type 1 diabetes (139,140). There is also some evidence that that onset of type 1 diabetes and focus on carbohydrates could be a precursor to disordered eating behaviors and preoccupation with food. In one longitudinal study of female children with type 1 diabetes, researchers found that 60% of the participants had developed an eating disorder by age 25 years (141). While eating disorders are less studied in males, at least for females, it appears that the onset of type 1 diabetes is associated with the development of eating disorders.

It is also important to note that the mechanisms of type 1 diabetes diagnosis may lead to body dissatisfaction and potentially to eating disorders. Often, when a person has type 1 diabetes that is undiagnosed and untreated, they will lose a large amount of body weight. Once diagnosed with type 1 diabetes and treated with insulin, many will gain weight quickly (142). In addition, studies have found that people who have type 1 diabetes and optimal A1C levels are higher weight on average compared to both those with diabetes and high A1C and age-matched people without diabetes (128).

While diabetes can predispose females to eating disorders in type 1 diabetes, the reverse seems to be true in type 2 diabetes. A meta-analysis found that both BED and bulimia nervosa were associated with the risk of later development of type 2 diabetes, while anorexia nervosa was not significantly associated (143).

### Treatment and Intervention for Eating Disorders

Treatments for eating disorders generally include such therapies as CBT or psychotherapy and/or nutritional counseling. According to a review of eating disorder treatments in those with type 1 diabetes, inpatient therapy was the most effective for treating eating disorders, but eating disorder interventions did not appear to affect A1C levels (144). For those with type 2 diabetes, medications and therapies appear to be effective for BED (145), and based on a pilot study, CBT may offer promise as an effective treatment for disordered eating behaviors in this population (146). More recently, a self-compassion intervention was developed and pilot tested among adolescents with type 1 diabetes (T1DE); the authors reported problems with feasibility, and efficacy was not evaluated (147).

For insulin restriction specifically, only one intervention has been tested in study of adolescent females with type 1 diabetes. This was a psychoeducational intervention with group sessions for both the adolescents and their parents, and results indicated that the treatment was effective for reducing disordered eating behaviors but not insulin restriction (148). While insulin restriction is generally treated the same way as other eating disorders, no recent trials of interventions have been conducted.

## Other Mental Health Diagnoses Among People With Diabetes

### Serious Mental Illness

Schizophrenia is a mental disorder characterized by disruptions in thought processes, perceptions, emotional responsiveness, and social interactions. Schizophrenia is typically chronic and severe, although the course varies among individuals. The annual prevalence is difficult to characterize; however, estimates suggest that in the United States between 0.25% and 0.64% of the population is affected by schizophrenia and related psychotic disorders (149). The incidence of schizophrenia is higher in males (150). Bipolar disorder is characterized by dramatic shifts in mood, energy, and activity levels that impact a person’s ability to function. The 12-month prevalence of bipolar disorder in the United States among adults is 2.8% and is roughly equal in men (2.9%) and women (2.8%) (151).

#### Prevalence of Diabetes in Individuals With Serious Mental Illness

Estimates from a range of meta-analyses capturing data from the United States and around the world suggest the prevalence of diabetes in adults with schizophrenia to be 1.82 to 2.53 times greater than that of the general population (152,153,154). Further, increasing age is associated with type 2 diabetes prevalence among individuals with schizophrenia (153,154). However, the true prevalence of diabetes among individuals with schizophrenia may be underestimated due to the competing demands of medical, economic, and social concerns faced by individuals with psychotic disorders, as well as the silent nature of diabetes (153).

#### Measurement, Treatment, and Causal Mechanisms

A primary cause of diabetes among people with severe mental illness is the medications used to treat psychiatric symptoms. The rate of type 2 diabetes among individuals prescribed first- or second-generation antipsychotic medications is higher than among individuals not prescribed either of these medication classes (155). Further, there is a rapid rise in type 2 diabetes following antipsychotic treatment initiation, suggesting that antipsychotics are related (155). Specifically, a meta-analysis found that among individuals with severe mental illness, the prevalence of type 2 diabetes more than tripled from before antipsychotic treatment (2.9%) to after antipsychotic treatment (11.3%) (156). Therefore, it is critically important to pay attention to diabetes risk factors among individuals prescribed antipsychotic medications.

Antipsychotic medications increase the risk for type 2 diabetes indirectly due to the weight gain associated with this class of medications and directly by adversely affecting insulin sensitivity and secretion (155). Side effects, including weight gain and changes to insulin sensitivity and secretion, further obscure the true prevalence of diabetes among people with schizophrenia. In fact, among youth, exposure to antipsychotic medications conferred a 2.5-fold increased risk for developing type 2 diabetes compared to no exposure to psychiatric medications and a twofold increased risk compared to youth taking nonantipsychotic psychiatric medications (157).

Controlling psychotic disorders is likely a necessary condition for addressing diabetes risk. However, this can be challenging as symptoms common to severe mental illness, such as disorganization and lack of routines, are counterproductive to successful management of diabetes. Treating diabetes in individuals with severe mental illness and type 2 diabetes should follow the same course as for those without severe mental illness. Given the compounding factors of weight gain, inactivity, and social isolation associated with severe mental illness, using medications that do not compound these risk factors is ideal (155). Finally, lifestyle interventions for weight gain in adults with severe mental illness have had moderate success but are intensive to deliver and may be difficult to implement widely (155). A small, single group study found delivering diabetes education in a psychiatric setting for adults with serious mental illness and diabetes improved glycemic management and body mass index alongside diabetes knowledge and self-care, with maintenance of A1C findings a year later (158).

### Substance-Related Disorders and Substance Abuse

The National Survey on Drug Use and Health suggests that, in 2022, 10.5% of people age ≥12 years in the United States had an alcohol use disorder (159) and 9.7% had a drug use disorder (160) in the last year. Overall, individuals with diabetes are significantly less likely to have substance use disorders (OR 0.63) than individuals without diabetes (74). Individuals with diabetes are also significantly less likely to have alcohol use disorders (OR 0.34), tobacco use disorders (OR 0.76), and cannabis use disorders (OR 0.36). There were no differences in other drug classes between individuals with and without diabetes (74). For adults with type 2 diabetes who do smoke, a review shows that quitting smoking is beneficial, despite possible weight gain associated with ceasing nicotine, given the increased mortality and accelerated rate of severe vascular complications in people with diabetes who smoke (161). When a substance use disorder is present, diabetes self-management is challenging (162), and more work may help to highlight this area of overlap.

## Conclusion

The research reviewed herein, summarized in Table 6, highlights the continued importance of assessing and treating psychosocial and behavioral health concerns among people with diabetes, as they are at increased risk for depression, anxiety, and eating disorders. The causes and consequences of these disorders in relation to diabetes are bidirectional: the chronic stress of managing diabetes may initiate or exacerbate symptoms, and those symptoms may interfere with people’s ability to effectively manage diabetes. Compounding the effects of psychosocial and behavioral health concerns is stigma, both about mental health concerns and about diabetes itself. Four in five adults with diabetes experience stigma about diabetes (163), and continued work may be beneficial to understand the multiple sources of stigma and how they might impact management and outcomes. It is also important to note that social determinants of health, such as food insecurity (164) and lack of health care coverage (58), are associated with both diabetes and psychosocial outcomes, and future work to systematically review these factors in relation to mental health in people with diabetes may increase our understanding (165). Findings from the current review demonstrate the continued need for screening and treatment of these behaviors and disorders among people with diabetes. Although substance use disorders are less common in people with diabetes compared to those without diabetes, when present, they represent a major barrier to effective diabetes care. Further work may be useful, especially in the context of increased availability and legality of cannabis.

## American Diabetes Association Mental Health Directory

https://my.diabetes.org/health-directory

## List of Abbreviations

A1C: glycated hemoglobin
BED: binge eating disorder
BRFSS: Behavioral Risk Factor Surveillance System
CBT: cognitive behavioral therapy or treatment
CDC: Centers for Disease Control and Prevention
CDI: Children’s Depression Inventory
CES-D: Center for Epidemiologic Studies Depression Scale
CGM: continuous glucose monitoring
CI: confidence interval
DDS: Diabetes Distress Scale
DEPS-R: Diabetes Eating Problem Survey – Revised
DKA: diabetic ketoacidosis
DSM-5-TR: Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition Text Revision
FoH: fear of hypoglycemia
FPG: fasting plasma glucose
MDD: major depressive disorder
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
OR: odds ratio
PAID: Problem Areas in Diabetes
PHQ: Patient Health Questionnaire
RCT: randomized control trial
SCID-5-RV: Structured Clinical Interview for the DSM
SEARCH: SEARCH for Diabetes in Youth study
SMD: standardized mean difference

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Glucose: mg/dL x 0.0555 = mmol/L

## Funding

Dr. Roddy was supported by the Vanderbilt Faculty Research Scholars (KL2TR002245).

## Acknowledgment

This is an update of: Gonzalez JS, Hood KK, Esbitt SA, Mukherji S, Kane NS, Jacobson A: Psychiatric and Psychosocial Issues Among Individuals Living with Diabetes. Chapter 33 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 33.1–33.34

## Article History

Received in final form on January 29, 2025.

## References

1 Gonzalez JS, Hood KK, Esbitt SA, Mukherji S, Kane NS, Jacobson A. Psychiatric and Psychosocial Issues Among Individuals Living With Diabetes. Diabetes in America 3rd ed. National Institutes of Health; 2018; 33.1-33.34:chap 33. https://www.ncbi.nlm.nih.gov/books/NBK567974/
2 Kroenke K, Spitzer RL, Williams JB. The PHQ-9: validity of a brief depression severity measure. J Gen Intern Med. 2001;16(9):606-613. doi:10.1046/j.1525-1497.2001.016009606.x 11556941
3 National Institute of Mental Health. Mental health information. Statistics. Major depression. Accessed July 18, 2024. https://www.nimh.nih.gov/health/statistics/major-depression
4 Hasin DS, Sarvet AL, Meyers JL, et al. Epidemiology of adult DSM-5 major depressive disorder and its specifiers in the United States. JAMA Psychiatry. 2018;75(4):336-346. doi:10.1001/jamapsychiatry.2017.4602 29450462
5 Kovacs M. The Children’s Depression Inventory (CDI). Psychopharmacol Bull. 1985;21(4):995-998.4089116
6 Radloff LS. The CES-D scale: a self-report depression scale for research in the general population. Applied Psychological Measurement. 1977;1(3):385-401. doi:10.1177/014662167700100306
7 First MB, Williams JBW, Karg RS, Spitzer RL. Structured Clinical Interview for DSM-5 Disorders—Clinician Version (SCID-5-CV). American Psychiatric Association Publishing; 2015.
8 Buchberger B, Huppertz H, Krabbe L, Lux B, Mattivi JT, Siafarikas A. Symptoms of depression and anxiety in youth with type 1 diabetes: a systematic review and meta-analysis. Psychoneuroendocrinology. 2016;70:70-84. doi:10.1016/j.psyneuen.2016.04.019 27179232
9 Marker AM, Patton SR, McDonough RJ, Feingold H, Simon L, Clements MA. Implementing clinic-wide depression screening for pediatric diabetes: an initiative to improve healthcare processes. Pediatr Diabetes. 2019;20(7):964-973. doi:10.1111/pedi.12886 31264763
10 Trief PM, Foster NC, Chaytor N, et al. Longitudinal changes in depression symptoms and glycemia in adults with type 1 diabetes. Diabetes Care. 2019;42(7):1194-1201. doi:10.2337/dc18-2441 31221694
11 Silverstein J, Cheng P, Ruedy KJ, et al. Depressive symptoms in youth with type 1 or type 2 diabetes: results of the Pediatric Diabetes Consortium Screening Assessment of Depression in Diabetes Study. Diabetes Care. 2015;38(12):2341-2343. doi:10.2337/dc15-0982 26459274
12 Substance Abuse and Mental Health Services Administration. 2022 National Survey on Drug Use and Health (NSDUH) Releases. 2022. https://www.samhsa.gov/data/release/2022-national-survey-drug-use-and-health-nsduh-releases#methodology
13 Elamoshy R, Bird Y, Thorpe L, Moraros J. Risk of depression and suicidality among diabetic patients: a systematic review and meta-analysis. J Clin Med. 2018;7(11):445. doi:10.3390/jcm7110445 30453557
14 Myers AK, Grannemann BD, Lingvay I, Trivedi MH. Brief report: depression and history of suicide attempts in adults with new-onset type 2 diabetes. Psychoneuroendocrinology. 2013;38(11):2810-2814. doi:10.1016/j.psyneuen.2013.06.013 23978666
15 Centers for Disease Control and Prevention. Youth Risk Behavior Survey Data Summary & Trends Report: 2013–2023. U.S. Department of Health and Human Services;2024.
16 Majidi S, O’Donnell HK, Stanek K, Youngkin E, Gomer T, Driscoll KA. Suicide risk assessment in youth and young adults with type 1 diabetes. Diabetes Care. 2020;43(2):343-348. doi:10.2337/dc19-0831 31822488
17 Moss AC, Roberts AJ, Yi-Frazier JP, et al. Identifying suicide risk in adolescents and young adults with type 1 diabetes: are depression screeners sufficient? Diabetes Care. 2022;45(5):1288-1291. doi:10.2337/dc21-1553 35147698
18 Mulvaney SA, Mara CA, Kichler JC, et al. A retrospective multisite examination of depression screening practices, scores, and correlates in pediatric diabetes care. Transl Behav Med. 2021;11(1):122-131. doi:10.1093/tbm/ibz171 31764981
19 Stuckey H, Fisher L, Polonsky WH, et al. Key factors for overcoming psychological insulin resistance: an examination of patient perspectives through content analysis. BMJ Open Diabetes Res Care. 2019;7(1):e000723. doi:10.1136/bmjdrc-2019-000723 31908792
20 Lawrence JM, Standiford DA, Loots B, et al. Prevalence and correlates of depressed mood among youth with diabetes: the SEARCH for Diabetes in Youth study. Pediatrics. 2006;117(4):1348-1358. doi:10.1542/peds.2005-1398 16585333
21 Hood KK, Beavers DP, Yi-Frazier J, et al. Psychosocial burden and glycemic control during the first 6 years of diabetes: results from the SEARCH for Diabetes in Youth study. J Adolesc Health. 2014;55(4):498-504. doi:10.1016/j.jadohealth.2014.03.011 24815959
22 Akbarizadeh M, Naderi Far M, Ghaljaei F. Prevalence of depression and anxiety among children with type 1 and type 2 diabetes: a systematic review and meta-analysis. World J Pediatr. 2022;18(1):16-26. doi:10.1007/s12519-021-00485-2 34807367
23 Beran M, Muzambi R, Geraets A, et al. The bidirectional longitudinal association between depressive symptoms and HbA(1c): a systematic review and meta-analysis. Diabet Med. 2022;39(2):e14671. doi:10.1111/dme.14671 34407250
24 Langberg J, Mueller A, Rodriguez de la Vega P, Castro G, Varella M. The association of hemoglobin A1c levels and depression among adults with diabetes in the United States. Cureus. 2022;14(2):e22688. doi:10.7759/cureus.22688 35386152
25 Glick BA, Hong KMC, Obrynba K, Kamboj MK, Hoffman RP. Identifying depressive symptoms among diabetes type and the impact on hemoglobin A1c. J Pediatr Endocrinol Metab. 2018;31(1):39-44. doi:10.1515/jpem-2017-0241 29303779
26 Picozzi A, DeLuca F. Depression and glycemic control in adolescent diabetics: evaluating possible association between depression and hemoglobin A1c. Public Health. 2019;170:32-37. doi:10.1016/j.puhe.2019.02.005 30904581
27 McCoy RG, Galindo RJ, Swarna KS, et al. Sociodemographic, clinical, and treatment-related factors associated with hyperglycemic crises among adults with type 1 or type 2 diabetes in the US from 2014 to 2020. JAMA Netw Open. 2021;4(9):e2123471. doi:10.1001/jamanetworkopen.2021.23471 34468753
28 Garey CJ, Clements MA, McAuliffe-Fogarty AH, et al. The association between depression symptom endorsement and glycemic outcomes in adolescents with type 1 diabetes. Pediatr Diabetes. 2022;23(2):248-257. doi:10.1111/pedi.13290 34779100
29 Pouwer F, Schram MT, Iversen MM, Nouwen A, Holt RIG. How 25 years of psychosocial research has contributed to a better understanding of the links between depression and diabetes. Diabet Med. 2020;37(3):383-392. doi:10.1111/dme.14227 31909844
30 Nouwen A, Adriaanse MC, van Dam K, et al. Longitudinal associations between depression and diabetes complications: a systematic review and meta-analysis. Diabet Med. 2019;36(12):1562-1572. doi:10.1111/dme.14054 31215077
31 Hamburger ER, Goethals ER, Choudhary A, Jaser SS. Sleep and depressive symptoms in adolescents with type 1 diabetes not meeting glycemic targets. Diabetes Res Clin Pract. 2020;169:108442. doi:10.1016/j.diabres.2020.108442 32941959
32 Substance Abuse and Mental Health Services Administration. Key substance use and mental health indicators in the United States. Results from the 2021 National Survey on Drug Use and Health. 2022. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. https://www.samhsa.gov/data/report/2021-nsduh-annual-national-report
33 de Groot M, Shubrook JH, Hornsby WG, Jr., et al. Program ACTIVE II: outcomes from a randomized, multistate community-based depression treatment for rural and urban adults with type 2 diabetes. Diabetes Care. 2019;42(7):1185-1193. doi:10.2337/dc18-2400 31221693
34 Roopan S, Larsen ER. Use of antidepressants in patients with depression and comorbid diabetes mellitus: a systematic review. Acta Neuropsychiatr. 2017;29(3):127-139. doi:10.1017/neu.2016.54 27776567
35 Hood KK, Iturralde E, Rausch J, Weissberg-Benchell J. Preventing diabetes distress in adolescents with type 1 diabetes: results 1 year after participation in the STePS program. Diabetes Care. 2018;41(8):1623-1630. doi:10.2337/dc17-2556 29921624
36 Young-Hyman D, de Groot M, Hill-Briggs F, Gonzalez JS, Hood K, Peyrot M. Psychosocial Care for People With Diabetes: a Position Statement of the American Diabetes Association. Diabetes Care. 2016;39(12):2126-2140. doi:10.2337/dc16-2053 27879358
37 Polonsky WH, Fisher L, Earles J, et al. Assessing psychosocial distress in diabetes: development of the Diabetes Distress Scale. Diabetes Care. 2005;28(3):626-631. doi:10.2337/diacare.28.3.626 15735199
38 Shapiro JB, Vesco AT, Weil LEG, Evans MA, Hood KK, Weissberg-Benchell J. Psychometric properties of the Problem Areas in Diabetes: Teen and Parent of Teen versions. J Pediatr Psychol. 2018;43(5):561-571. doi:10.1093/jpepsy/jsx146 29267939
39 Evans MA, Weil LEG, Shapiro JB, et al. Psychometric properties of the parent and child problem areas in diabetes measures. J Pediatr Psychol. 2019;44(6):703-713. doi:10.1093/jpepsy/jsz018 30920628
40 Hessler D, Fisher L, Polonsky W, Johnson N. Understanding the areas and correlates of diabetes-related distress in parents of teens with type 1 diabetes. J Pediatr Psychol. 2016;41(7):750-758. doi:10.1093/jpepsy/jsw002 26869664
41 Kovacs Burns K, Nicolucci A, Holt RI, et al. Diabetes Attitudes, Wishes and Needs second study (DAWN2): cross-national benchmarking indicators for family members living with people with diabetes. Diabet Med. 2013;30(7):778-788. doi:10.1111/dme.12239 23701236
42 Polonsky WH, Anderson BJ, Lohrer PA, et al. Assessment of diabetes-related distress. Diabetes Care. 1995;18(6):754-760. doi:10.2337/diacare.18.6.754 7555499
43 Fisher L, Gonzalez JS, Polonsky WH. The confusing tale of depression and distress in patients with diabetes: a call for greater clarity and precision. Diabet Med. 2014;31(7):764-772. doi:10.1111/dme.12428 24606397
44 Fisher L, Glasgow RE, Mullan JT, Skaff MM, Polonsky WH. Development of a brief diabetes distress screening instrument. Ann Fam Med. 2008;6(3):246-252. doi:10.1370/afm.842 18474888
45 McGuire BE, Morrison TG, Hermanns N, et al. Short-form measures of diabetes-related emotional distress: the Problem Areas in Diabetes Scale (PAID)-5 and PAID-1. Diabetologia. 2010;53(1):66-69. doi:10.1007/s00125-009-1559-5 19841892
46 Fisher L, Polonsky W, Naranjo D, Strycker L, Hessler D. A novel approach to understanding and assessing the emotional side of type 1 diabetes: the Type 1-Diabetes Distress Assessment System. Diabet Med. 2024;41(7):e15282. doi:10.1111/dme.15282 38244209
47 Perrin NE, Davies MJ, Robertson N, Snoek FJ, Khunti K. The prevalence of diabetes-specific emotional distress in people with type 2 diabetes: a systematic review and meta-analysis. Diabet Med. 2017;34(11):1508-1520. doi:10.1111/dme.13448 28799294
48 Hagger V, Hendrieckx C, Sturt J, Skinner TC, Speight J. Diabetes distress among adolescents with type 1 diabetes: a systematic review. Curr Diab Rep. 2016;16(1):9. doi:10.1007/s11892-015-0694-2 26748793
49 Fisher L, Hessler D, Polonsky W, Strycker L, Masharani U, Peters A. Diabetes distress in adults with type 1 diabetes: prevalence, incidence and change over time. J Diabetes Complications. 2016;30(6):1123-1128. doi:10.1016/j.jdiacomp.2016.03.032 27118163
50 Fisher L, Polonsky WH, Hessler DM, et al. Understanding the sources of diabetes distress in adults with type 1 diabetes. J Diabetes Complications. 2015;29(4):572-577. doi:10.1016/j.jdiacomp.2015.01.012 25765489
51 Evans M, Ellis DA, Vesco AT, et al. Diabetes distress in urban Black youth with type 1 diabetes and their caregivers: associations with glycemic control, depression, and health behaviors. J Pediatr Psychol. 2024;49(6):394-404. doi:10.1093/jpepsy/jsad096 38216126
52 Helgeson VS, Naqvi JB, Korytkowski MT, Gary-Webb TL. A closer look at racial differences in diabetes outcomes among a community sample: diabetes distress, self-care, and HbA1c. Diabetes Care. 2021;44(11):2487-2492. doi:10.2337/dc21-0734 34475029
53 Williams IC, Clay OJ, Ovalle F, Atkinson D, Crowe M. The role of perceived discrimination and other psychosocial factors in explaining diabetes distress among older African American and White adults. J Appl Gerontol. 2020;39(1):99-104. doi:10.1177/0733464817750273 29291677
54 Nouwen A, Urquhart Law G, Hussain S, McGovern S, Napier H. Comparison of the role of self-efficacy and illness representations in relation to dietary self-care and diabetes distress in adolescents with type 1 diabetes. Psychol Health. 2009;24(9):1071-1084. doi:10.1080/08870440802254597 20205046
55 Skinner TC, Joensen L, Parkin T. Twenty-five years of diabetes distress research. Diabet Med. 2020;37(3):393-400. doi:10.1111/dme.14157 31638279
56 Hong KMC, Glick BA, Kamboj MK, Hoffman RP. Glycemic control, depression, diabetes distress among adolescents with type 1 diabetes: effects of sex, race, insurance, and obesity. Acta Diabetol. 2021;58(12):1627-1635. doi:10.1007/s00592-021-01768-w 34213654
57 Inverso H, LeStourgeon LM, Parmar A, et al. Demographic and glycemic factors linked with diabetes distress in teens with type 1 diabetes. J Pediatr Psychol. 2022;47(9):1081-1089. doi:10.1093/jpepsy/jsac049 35656859
58 Trief PM, Uschner D, Tung M, et al. Diabetes distress in young adults with youth-onset type 2 diabetes: TODAY2 study results. Diabetes Care. 2022;45(3):529-537. doi:10.2337/dc21-1689 35015056
59 Mathiesen AS, Egerod I, Jensen T, Kaldan G, Langberg H, Thomsen T. Psychosocial interventions for reducing diabetes distress in vulnerable people with type 2 diabetes mellitus: a systematic review and meta-analysis. Diabetes Metab Syndr Obes. 2018;12:19-33. doi:10.2147/DMSO.S179301 30588053
60 Hessler DM, Fisher L, Guzman S, et al. EMBARK: a randomized, controlled trial comparing three approaches to reducing diabetes distress and improving HbA1c in adults with type 1 diabetes. Diabetes Care. 2024;47(8):1370-1378. doi:10.2337/dc23-2452 38809903
61 Yi-Frazier JP, Hilliard ME, O’Donnell MB, et al. Promoting resilience in stress management for adolescents with type 1 diabetes: a randomized clinical trial. JAMA Netw Open. 2024;7(8):e2428287. doi:10.1001/jamanetworkopen.2024.28287 39158914
62 American Psychological Association. Diagnostic and Statistical Manual of Mental Disorders. 5th ed. Text Revision. American Psychiatric Publishing; 2022.
63 Simpson HB, Neria Y, Lewis-Fernández R, Schneier F. Anxiety Disorders: Theory, Research and Clinical Perspectives. Cambridge University Press; 2010.
64 National Institute of Mental Health. Mental health information. Statistics. Any anxiety disorder. Accessed February 20, 2024. https://www.nimh.nih.gov/health/statistics/any-anxiety-disorder
65 Remes O, Brayne C, van der Linde R, Lafortune L. A systematic review of reviews on the prevalence of anxiety disorders in adult populations. Brain Behav. 2016;6(7):e00497. doi:10.1002/brb3.497 27458547
66 National Institute of Mental Health. Mental health information. Statistics. Generalized anxiety disorder. https://www.nimh.nih.gov/health/statistics/generalized-anxiety-disorder
67 National Institute of Mental Health. Mental health information. Statistics. Panic disorder. Accessed February 20, 2024. https://www.nimh.nih.gov/health/statistics/panic-disorder
68 National Institute of Mental Health. Mental health information. Statistics. Specific phobia. Accessed February 20, 2024. https://www.nimh.nih.gov/health/statistics/specific-phobia
69 Spitzer RL, Kroenke K, Williams JB, Löwe B. A brief measure for assessing generalized anxiety disorder: the GAD-7. Arch Intern Med. 2006;166(10):1092-1097. doi:10.1001/archinte.166.10.1092 16717171
70 Brown TA, Chorpita BF, Korotitsch W, Barlow DH. Psychometric properties of the Depression Anxiety Stress Scales (DASS) in clinical samples. Behav Res Ther. 1997;35(1):79-89. doi:10.1016/s0005-7967(96)00068-x 9009048
71 Cox DJ, Irvine A, Gonder-Frederick L, Nowacek G, Butterfield J. Fear of hypoglycemia: quantification, validation, and utilization. Diabetes Care. 1987;10(5):617-621. doi:10.2337/diacare.10.5.617 3677982
72 Sherr JL, Laffel LM, Liu J, et al. Severe hypoglycemia and impaired awareness of hypoglycemia persist in people with type 1 diabetes despite use of diabetes technology: results from a cross-sectional survey. Diabetes Care. 2024;47(6):941-947. doi:10.2337/dc23-1765 38295397
73 Amiri S, Behnezhad S. Diabetes and anxiety symptoms: a systematic review and meta-analysis. Int J Psychiatry Med. 2019:91217419837407. doi:10.1177/0091217419837407 30939958
74 Boden MT. Prevalence of mental disorders and related functioning and treatment engagement among people with diabetes. J Psychosom Res. 2018;106:62-69. doi:10.1016/j.jpsychores.2018.01.001 29455901
75 Subasinghe S, Bongetti E, O’Brien CL, et al. A review of the prevalence and associations of depression and anxiety in type 1 diabetes mellitus. J Diabetes Metab Disord. 2015;2:007. doi:10.24966/DMD-201X/100007
76 Przezak A, Bielka W, Molęda P. Fear of hypoglycemia—an underestimated problem. Brain Behav. 2022;12(7):e2633. doi:10.1002/brb3.2633 35620854
77 Krawczyk J, Duda-Sobczak A, Zozulińska-Ziółkiewicz D. Fear of hypoglycaemia—from normality to pathology. Diagnostic criteria and therapeutic directions. Clin Diabetol. 2020;9(6):487-492. doi:10.5603/DK.2020.0046
78 Peter ME, Rioles N, Liu J, et al. Prevalence of fear of hypoglycemia in adults with type 1 diabetes using a newly developed screener and clinician’s perspective on its implementation. BMJ Open Diabetes Res Care. 2023;11(4):e003394. doi:10.1136/bmjdrc-2023-003394 37423638
79 Hajós TR, Polonsky WH, Pouwer F, Gonder-Frederick L, Snoek FJ. Toward defining a cutoff score for elevated fear of hypoglycemia on the Hypoglycemia Fear Survey Worry subscale in patients with type 2 diabetes. Diabetes Care. 2014;37(1):102-108. doi:10.2337/dc13-0971 23990513
80 Monaghan MC, Hilliard ME, Cogen FR, Streisand R. Nighttime caregiving behaviors among parents of young children with type 1 diabetes: associations with illness characteristics and parent functioning. Fam Syst Health. 2009;27(1):28-38. doi:10.1037/a0014770 19630443
81 Mollema ED, Snoek FJ, Heine RJ, van der Ploeg HM. Phobia of self-injecting and self-testing in insulin-treated diabetes patients: opportunities for screening. Diabet Med. 2001;18(8):671-674. doi:10.1046/j.1464-5491.2001.00547.x 11553207
82 Fu AZ, Qiu Y, Radican L. Impact of fear of insulin or fear of injection on treatment outcomes of patients with diabetes. Curr Med Res Opin. 2009;25(6):1413-1420. doi:10.1185/03007990902905724 19422281
83 Mollema ED, Snoek FJ, Adèr HJ, Heine RJ, van der Ploeg HM. Insulin-treated diabetes patients with fear of self-injecting or fear of self-testing: psychological comorbidity and general well-being. J Psychosom Res. 2001;51(5):665-672. doi:10.1016/s0022-3999(01)00229-x 11728507
84 Bernstein CM, Stockwell MS, Gallagher MP, Rosenthal SL, Soren K. Mental health issues in adolescents and young adults with type 1 diabetes: prevalence and impact on glycemic control. Clin Pediatr (Phila). 2013;52(1):10-15. doi:10.1177/0009922812459950 22988007
85 Rechenberg K, Whittemore R, Grey M. Anxiety in youth with type 1 diabetes. J Pediatr Nurs. 2017;32:64-71. doi:10.1016/j.pedn.2016.08.007 27663096
86 Al Hayek AA, Robert AA, Babli S, Almonea K, Al Dawish MA. Fear of self-injecting and self-testing and the related risk factors in adolescents with type 1 diabetes: a cross-sectional study. Diabetes Ther. 2017;8(1):75-83. doi:10.1007/s13300-016-0221-8 27995595
87 Gonder-Frederick L. Fear of hypoglycemia: a review. Diabetic Hypoglycemia. 2013;5(3):3-11. Available from: https://www.hypodiab.com/article.aspx?volumeID=15&issueID=24&articleID=131
88 Grigsby AB, Anderson RJ, Freedland KE, Clouse RE, Lustman PJ. Prevalence of anxiety in adults with diabetes: a systematic review. J Psychosom Res. 2002;53(6):1053-1060. doi:10.1016/s0022-3999(02)00417-8 12479986
89 Woon L, Autar Singh GK, Sidi H. Does personality and anxiety symptomatology matter in the diabetes mellitus treatment adherence? A cross-sectional study among women with diabetes mellitus. IIUM Medical Journal Malaysia. 2021;20(4):1. doi:10.31436/imjm.v20i4.1911
90 Aujla N, Davies MJ, Skinner TC, et al. The association between anxiety and measures of glycaemia in a population-based diabetes screening programme. Diabet Med. 2011;28(7):785-788. doi:10.1111/j.1464-5491.2011.03245.x 21672003
91 McDade-Montez EA, Watson D. Examining the potential influence of diabetes on depression and anxiety symptoms via multiple sample confirmatory factor analysis. Ann Behav Med. 2011;42(3):341-351. doi:10.1007/s12160-011-9298-5 21833822
92 Chlebowy DO, Batscha C, Kubiak N, Crawford T. Relationships of depression, anxiety, and stress with adherence to self-management behaviors and diabetes measures in African American adults with type 2 diabetes. J Racial Ethn Health Disparities. 2019;6(1):71-76. doi:10.1007/s40615-018-0500-3 29845520
93 Anderson RJ, Grigsby AB, Freedland KE, et al. Anxiety and poor glycemic control: a meta-analytic review of the literature. Int J Psychiatry Med. 2002;32(3):235-247. doi:10.2190/KLGD-4H8D-4RYL-TWQ8 12489699
94 Smith KJ, Deschênes SS, Schmitz N. Investigating the longitudinal association between diabetes and anxiety: a systematic review and meta-analysis. Diabet Med. 2018;35(6):677-693. doi:10.1111/dme.13606 29460506
95 Khambaty T, Callahan CM, Perkins AJ, Stewart JC. Depression and anxiety screens as simultaneous predictors of 10-year incidence of diabetes mellitus in older adults in primary care. J Am Geriatr Soc. 2017;65(2):294-300. doi:10.1111/jgs.14454 27641686
96 Hackett RA, Steptoe A. Type 2 diabetes mellitus and psychological stress—a modifiable risk factor. Nat Rev Endocrinol. 2017;13(9):547-560. doi:10.1038/nrendo.2017.64 28664919
97 Joseph JJ, Golden SH. Cortisol dysregulation: the bidirectional link between stress, depression, and type 2 diabetes mellitus. Ann N Y Acad Sci. 2017;1391(1):20-34. doi:10.1111/nyas.13217 27750377
98 Dutheil S, Ota KT, Wohleb ES, Rasmussen K, Duman RS. High-fat diet induced anxiety and anhedonia: impact on brain homeostasis and inflammation. Neuropsychopharmacology. 2016;41(7):1874-1887. doi:10.1038/npp.2015.357 26658303
99 Vorspan F, Mehtelli W, Dupuy G, Bloch V, Lépine JP. Anxiety and substance use disorders: co-occurrence and clinical issues. Curr Psychiatry Rep. 2015;17(2):4. doi:10.1007/s11920-014-0544-y 25617040
100 Abraham S, Shah NG, Diez Roux A, et al. Trait anger but not anxiety predicts incident type 2 diabetes: the Multi-Ethnic Study of Atherosclerosis (MESA). Psychoneuroendocrinology. 2015;60:105-113. doi:10.1016/j.psyneuen.2015.06.007 26142567
101 Surwit RS, van Tilburg MA, Zucker N, et al. Stress management improves long-term glycemic control in type 2 diabetes. Diabetes Care. 2002;25(1):30-34. doi:10.2337/diacare.25.1.30 11772897
102 Wagner JA, Bermudez-Millan A, Damio G, et al. A randomized, controlled trial of a stress management intervention for Latinos with type 2 diabetes delivered by community health workers: outcomes for psychological wellbeing, glycemic control, and cortisol. Diabetes Res Clin Pract. 2016;120:162-170. doi:10.1016/j.diabres.2016.07.022 27568646
103 Noordali F, Cumming J, Thompson JL. Effectiveness of mindfulness-based interventions on physiological and psychological complications in adults with diabetes: a systematic review. J Health Psychol. 2017;22(8):965-983. doi:10.1177/1359105315620293 26721631
104 Innes KE, Selfe TK. Yoga for adults with type 2 diabetes: a systematic review of controlled trials. J Diabetes Res. 2016;2016:6979370. doi:10.1155/2016/6979370 26788520
105 Bickett A, Tapp H. Anxiety and diabetes: innovative approaches to management in primary care. Exp Biol Med (Maywood). 2016;241(15):1724-1731. doi:10.1177/1535370216657613 27390262
106 Polonsky WH, Hessler D, Ruedy KJ, Beck RW, DIAMOND Study Group. The impact of continuous glucose monitoring on markers of quality of life in adults with type 1 diabetes: further findings from the DIAMOND randomized clinical trial. Diabetes Care. 2017;40(6):736-741. doi:10.2337/dc17-0133 28389582
107 Cox D, Mohr DC. Managing difficulties with adherence to injectable medications due to blood, injection, and injury phobia and self-injection anxiety. Am J Drug Deliv. 2003;1(3):215-221. doi:10.2165/00137696-200301030-00005
108 Martyn-Nemeth P, Duffecy J, Quinn L, et al. FREE: a randomized controlled feasibility trial of a cognitive behavioral therapy and technology-assisted intervention to reduce fear of hypoglycemia in young adults with type 1 diabetes. J Psychosom Res. 2024;181:111679. doi:10.1016/j.jpsychores.2024.111679 38677235
109 Briery BG, Rabian B. Psychosocial changes associated with participation in a pediatric summer camp. J Pediatr Psychol. 1999;24(2):183-190. doi:10.1093/jpepsy/24.2.183 10361401
110 Hains AA, Davies WH, Parton E, Silverman AH. Brief report: a cognitive behavioral intervention for distressed adolescents with type I diabetes. J Pediatr Psychol. 2001;26(1):61-66. doi:10.1093/jpepsy/26.1.61 11145733
111 Diabetes Research in Children Network (DirecNet) Study Group. Psychological aspects of continuous glucose monitoring in pediatric type 1 diabetes. Pediatr Diabetes. 2006;7(1):32-38. doi:10.1111/j.1399-543X.2006.00142.x 16489972
112 Nefs G, Hendrieckx C, Reddy P, et al. Comorbid elevated symptoms of anxiety and depression in adults with type 1 or type 2 diabetes: results from the international diabetes MILES Study. J Diabetes Complications. 2019;33(8):523-529. doi:10.1016/j.jdiacomp.2019.04.013 31129003
113 National Institute of Mental Health. Mental health information. Statistics. Eating disorders. Accessed April 4, 2024. http://www.nimh.nih.gov/health/statistics/prevalence/eating-disorders-among-adults-anorexia-nervosa.shtml
114 Deloitte Access Economics. The social and economic cost of eating disorders in the United States of America: a report for the Strategic Training Initiative for the Prevention of Eating Disorders and the Academy for Eating Disorders. 2020. https://www.hsph.harvard.edu/striped/report-economic-costs-of-eating-disorders/
115 Garner DM, Olmsted MP, Bohr Y, Garfinkel PE. The Eating Attitudes Test: psychometric features and clinical correlates. Psychol Med. 1982;12(4):871-878. doi:10.1017/s0033291700049163 6961471
116 Young-Hyman DL, Davis CL. Disordered eating behavior in individuals with diabetes: importance of context, evaluation, and classification. Diabetes Care. 2010;33(3):683-689. doi:10.2337/dc08-1077 20190297
117 Markowitz JT, Butler DA, Volkening LK, Antisdel JE, Anderson BJ, Laffel LM. Brief screening tool for disordered eating in diabetes: internal consistency and external validity in a contemporary sample of pediatric patients with type 1 diabetes. Diabetes Care. 2010;33(3):495-500. doi:10.2337/dc09-1890 20032278
118 Rajkumar SV. The high cost of insulin in the United States: an urgent call to action. Mayo Clin Proc. 2020;95(1):22-28. doi:10.1016/j.mayocp.2019.11.013 31902423
119 Young V, Eiser C, Johnson B, et al. Eating problems in adolescents with type 1 diabetes: a systematic review with meta-analysis. Diabet Med. 2013;30(2):189-198. doi:10.1111/j.1464-5491.2012.03771.x 22913589
120 Yu Z, Muehleman V. Eating disorders and metabolic diseases. Int J Environ Res Public Health. 2023;20(3):2446. doi:10.3390/ijerph20032446 36767812
121 Winston AP. Eating disorders and diabetes. Curr Diab Rep. 2020;20(8):32. doi:10.1007/s11892-020-01320-0 32537669
122 Goodwin RD, Hoven CW, Spitzer RL. Diabetes and eating disorders in primary care. Int J Eat Disord. 2003;33(1):85-91. doi:10.1002/eat.10106 12474203
123 Beam AB, Weiebe DJ. Are there subtypes of insulin restriction among individuals with diabetes? A systematic review. Annals of Behavioral Medicine. 2023;57(Suppl_1):S449. doi:10.1093/abm/kaad011
124 Pursey KM, Hart M, Jenkins L, McEvoy M, Smart CE. Screening and identification of disordered eating in people with type 1 diabetes: a systematic review. J Diabetes Complications. 2020;34(4):107522. doi:10.1016/j.jdiacomp.2020.107522 31928891
125 Nip ASY, Reboussin BA, Dabelea D, et al. Disordered eating behaviors in youth and young adults with type 1 or type 2 diabetes receiving insulin therapy: the SEARCH for Diabetes in Youth study. Diabetes Care. 2019;42(5):859-866. doi:10.2337/dc18-2420 30862656
126 Mannucci E, Rotella F, Ricca V, Moretti S, Placidi GF, Rotella CM. Eating disorders in patients with type 1 diabetes: a meta-analysis. J Endocrinol Invest. 2005;28(5):417-419. doi:10.1007/BF03347221 16075924
127 Niemelä PE, Leppänen HA, Voutilainen A, et al. Prevalence of eating disorder symptoms in people with insulin-dependent-diabetes: a systematic review and meta-analysis. Eat Behav. 2024;53:101863. doi:10.1016/j.eatbeh.2024.101863 38452627
128 Broadley MM, Zaremba N, Andrew B, et al. 25 years of psychological research investigating disordered eating in people with diabetes: what have we learnt? Diabet Med. 2020;37(3):401-408. doi:10.1111/dme.14197 31797439
129 Hanlan ME, Griffith J, Patel N, Jaser SS. Eating disorders and disordered eating in type 1 diabetes: prevalence, screening, and treatment options. Curr Diab Rep. 2013;13:909-916. doi:10.1007/s11892-013-0418-4 24022608
130 Priesterroth L, Grammes J, Clauter M, Kubiak T. Diabetes technologies in people with type 1 diabetes mellitus and disordered eating: a systematic review on continuous subcutaneous insulin infusion, continuous glucose monitoring and automated insulin delivery. Diabet Med. 2021;38(7):e14581. doi:10.1111/dme.14581 33826771
131 Cunha MCSO, Dutra FCS, Brito LMMC, et al. Disordered eating behaviour and eating disorder among adolescents with type 1 diabetes: an integrative review. World J Meta-Anal. 2022;10(5):244-254. doi:10.13105/wjma.v10.i5.244
132 Moskovich AA, Dmitrieva NO, Babyak MA, et al. Real-time predictors and consequences of binge eating among adults with type 1 diabetes. J Eat Disord. 2019;7:7. doi:10.1186/s40337-019-0237-3 30923613
133 Presseller EK, Patarinski AGG, Zhang F, et al. Glucose variability: a physiological correlate of eating disorder behaviors among individuals with binge-spectrum eating disorders. Int J Eat Disord. 2022;55(12):1788-1798. doi:10.1002/eat.23838 36305323
134 Gibbings NK, Kurdyak PA, Colton PA, Shah BR. Diabetic ketoacidosis and mortality in people with type 1 diabetes and eating disorders. Diabetes Care. 2021;44(8):1783-1787. doi:10.2337/dc21-0517 34172488
135 Ikeda T, Takahashi T, Sato A, et al. Predictors of outcome in hypoglycemic encephalopathy. Diabetes Res Clin Pract. 2013;101(2):159-163. doi:10.1016/j.diabres.2013.05.007 23820485
136 Jones TW, McCarthy G, Tamborlane WV, et al. Mild hypoglycemia and impairment of brain stem and cortical evoked potentials in healthy subjects. Diabetes. 1990;39(12):1550-1555. doi:10.2337/diab.39.12.1550 2245879
137 Beam AB, Wiebe DJ. A systematic review of insulin restriction in diabetes management: what do we know about subtypes of insulin restriction? Oral presentation presented at: Society of Behavioral Medicine 44th Annual Meeting and Scientific Sessions; April 28, 2023; Phoenix, AZ.
138 Goebel-Fabbri AE, Fikkan J, Franko DL, Pearson K, Anderson BJ, Weinger K. Insulin restriction and associated morbidity and mortality in women with type 1 diabetes. Diabetes Care. 2008;31(3):415-419. doi:10.2337/dc07-2026 18070998
139 Neumark-Sztainer D, Patterson J, Mellin A, et al. Weight control practices and disordered eating behaviors among adolescent females and males with type 1 diabetes: associations with sociodemographics, weight concerns, familial factors, and metabolic outcomes. Diabetes Care. 2002;25(8):1289-1296. doi:10.2337/diacare.25.8.1289 12145223
140 Rodin G, Olmsted MP, Rydall AC, et al. Eating disorders in young women with type 1 diabetes mellitus. J Psychosom Res. 2002;53(4):943-949. doi:10.1016/s0022-3999(02)00305-7 12377307
141 Colton PA, Olmsted MP, Daneman D, et al. Eating disorders in girls and women with type 1 diabetes: a longitudinal study of prevalence, onset, remission, and recurrence. Diabetes Care. 2015;38(7):1212-1217. doi:10.2337/dc14-2646 25887359
142 Gregg B, Connor CG, Ruedy KJ, et al. Body mass index changes in youth in the first year after type 1 diabetes diagnosis. J Pediatr. 2015;166(5):1265-1269.e1. doi:10.1016/j.jpeds.2015.02.036 25919735
143 Nieto-Martínez R, González-Rivas JP, Medina-Inojosa JR, Florez H. Are eating disorders risk factors for type 2 diabetes? A systematic review and meta-analysis. Curr Diab Rep. 2017;17(12):138. doi:10.1007/s11892-017-0949-1 29168047
144 Clery P, Stahl D, Ismail K, Treasure J, Kan C. Systematic review and meta-analysis of the efficacy of interventions for people with type 1 diabetes mellitus and disordered eating. Diabet Med. 2017;34(12):1667-1675. doi:10.1111/dme.13509 28887815
145 Harris SR, Carrillo M, Fujioka K. Binge-eating disorder and type 2 diabetes: a review. Endocr Pract. 2021;27(2):158-164. doi:10.1016/j.eprac.2020.10.005 33554873
146 Vela AM, Palmer B, Gil-Rivas V, Cachelin F. The role of disordered eating in type 2 diabetes: a pilot study. Am J Lifestyle Med. 2021;17(1):131-139. doi:10.1177/15598276211002459 36636384
147 Boggiss AL, Consedine NS, Schache KR, et al. A brief self-compassion intervention for adolescents with type 1 diabetes and disordered eating: a feasibility study. Diabet Med. 2020;37(11):1854-1860. doi:10.1111/dme.14352 32614482
148 Olmsted MP, Daneman D, Rydall AC, Lawson ML, Rodin G. The effects of psychoeducation on disturbed eating attitudes and behavior in young women with type 1 diabetes mellitus. Int J Eat Disord. 2002;32(2):230-239. doi:10.1002/eat.10068 12210667
149 National Institute of Mental Health. Mental health information. Statistics. Schizophrenia. Accessed May 17, 2024. https://www.nimh.nih.gov/health/statistics/schizophrenia
150 Ochoa S, Usall J, Cobo J, Labad X, Kulkarni J. Gender differences in schizophrenia and first-episode psychosis: a comprehensive literature review. Schizophr Res Treatment. 2012;2012(1):916198. doi:10.1155/2012/916198 22966451
151 National Institute of Mental Health. Mental health information. Statistics. Bipolar disorder. Accessed May 17, 2024. https://www.nimh.nih.gov/health/statistics/bipolar-disorder
152 Annamalai A, Kosir U, Tek C. Prevalence of obesity and diabetes in patients with schizophrenia. World J Diabetes. 2017;8(8):390-396. doi:10.4239/wjd.v8.i8.390 28861176
153 Stubbs B, Vancampfort D, De Hert M, Mitchell AJ. The prevalence and predictors of type two diabetes mellitus in people with schizophrenia: a systematic review and comparative meta-analysis. Acta Psychiatr Scand. 2015;132(2):144-157. doi:10.1111/acps.12439 25943829
154 Huang CJ, Hsieh HM, Tu HP, Jiang HJ, Wang PW, Lin CH. Schizophrenia in type 2 diabetes mellitus: prevalence and clinical characteristics. Eur Psychiatry. 2018;54:102-108. doi:10.1016/j.eurpsy.2018.08.002 30193140
155 Holt RIG. Association between antipsychotic medication use and diabetes. Curr Diab Rep. 2019;19(10):96. doi:10.1007/s11892-019-1220-8 31478094
156 Vancampfort D, Correll CU, Galling B, et al. Diabetes mellitus in people with schizophrenia, bipolar disorder and major depressive disorder: a systematic review and large scale meta-analysis. World Psychiatry. 2016;15(2):166-174. doi:10.1002/wps.20309 27265707
157 Galling B, Roldán A, Nielsen RE, et al. Type 2 diabetes mellitus in youth exposed to antipsychotics: a systematic review and meta-analysis. JAMA Psychiatry. 2016;73(3):247-259. doi:10.1001/jamapsychiatry.2015.2923 26792761
158 Schnitzer K, Cather C, Thorndike AN, et al. Improved glycemic control in adults with serious mental illness and diabetes with a behavioral and educational intervention. Psychiatr Serv. 2020;71(7):730-733. doi:10.1176/appi.ps.201900336 32321387
159 SAMHSA, Center for Behavioral Health Statistics and Quality. National Survey on Drug Use and Health, 2021 and 2022. Table 5.9B – Alcohol Use Disorder in Past Year: Among People Aged 12 or Older; by Age Group and Demographic Characteristics, Percentages, 2021 and 2022. Accessed June 11, 2024. https://www.samhsa.gov/data/sites/default/files/reports/rpt42728/NSDUHDetailedTabs2022/NSDUHDetailedTabs2022/NSDUHDetTabsSect5pe2022.htm#tab5.9a
160 SAMHSA, Center for Behavioral Health Statistics and Quality. National Survey on Drug Use and Health, 2021 and 2022. Table 5.11B – Drug Use Disorder in Past Year: Among People Aged 12 or Older; by Age Group and Geographic and Socioeconomic Characteristics, Percentages, 2021 and 2022. Accessed June 11, 2024. https://www.samhsa.gov/data/sites/default/files/reports/rpt42728/NSDUHDetailedTabs2022/NSDUHDetailedTabs2022/NSDUHDetTabsSect5pe2022.htm#tab5.9a
161 Kos K. Cardiometabolic morbidity and mortality with smoking cessation, review of recommendations for people with diabetes and obesity. Curr Diab Rep. 2020;20(12):82. doi:10.1007/s11892-020-01352-6 33289870
162 Walter KN, Wagner JA, Cengiz E, Tamborlane WV, Petry NM. Substance use disorders among patients with type 2 diabetes: a dangerous but understudied combination. Curr Diab Rep. 2017;17(1):2. doi:10.1007/s11892-017-0832-0 28101793
163 Speight J, Holmes-Truscott E, Garza M, et al. Bringing an end to diabetes stigma and discrimination: an international consensus statement on evidence and recommendations. Lancet Diabetes Endocrinol. 2024;12(1):61-82. doi:10.1016/S2213-8587(23)00347-9 38128969
164 Silverman J, Krieger J, Kiefer M, Hebert P, Robinson J, Nelson K. The relationship between food insecurity and depression, diabetes distress and medication adherence among low-income patients with poorly-controlled diabetes. J Gen Intern Med. 2015;30(10):1476-1480. doi:10.1007/s11606-015-3351-1 25917659
165 Hill-Briggs F, Adler NE, Berkowitz SA, et al. Social determinants of health and diabetes: a scientific review. Diabetes Care. 2020;44(1):258-279. doi:10.2337/dci20-0053 33139407

TABLE 1.

Prevalence of Lifetime Diagnosis for Depression in Adults Age ≥18 Years, by Diabetes Status, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | N | Percent (SE) | N | Percent (SE)
Total | 60,755 | 25.4 (0.4)* | 380,805 | 20.0 (0.1)
Age (years)
18–34 | 1,401 | 43.8 (2.9)* | 72,543 | 24.7 (0.3)
35–49 | 3,255 | 33.8 (1.7)* | 55,470 | 20.4 (0.3)
50–64 | 21,816 | 27.9 (0.6)* | 126,739 | 18.5 (0.2)
≥65 | 34,283 | 19.5 (0.5)* | 126,053 | 14.2 (0.2)
Sex
Men | 30,028 | 19.0 (0.5)* | 177,359 | 14.3 (0.2)
Women | 30,727 | 32.0 (0.6)* | 203,446 | 25.3 (0.2)
Race and ethnicity
Non-Hispanic White | 43,027 | 27.6 (0.5)* | 288,038 | 22.2 (0.2)
Non-Hispanic Black | 7,082 | 21.9 (1.1)* | 28,476 | 15.6 (0.4)
Hispanic | 6,078 | 22.9 (1.1)* | 36,484 | 16.8 (0.4)
Non-Hispanic Asian | 1,406 | 12.9 (2.1) | 11,922 | 10.1 (0.6)
Non-Hispanic American Indian/ Alaska Native | 1,412 | 24.9 (2.9) | 5,623 | 23.5 (1.2)
Other^†^ | 1,750 | 38.2 (2.8)* | 10,262 | 27.8 (0.9)
Type of diabetes^‡^
Type 1 | 1,040 | 29.9 (2.4) | N/A | N/A
Type 2, use of insulin | 3,344 | 28.1 (1.3) | N/A | N/A
Type 2, no insulin | 7,112 | 23.8 (0.8) | N/A | N/A

All data are self-reported. N/A, not applicable; SE, standard error.

* p<0.001 compared to no diabetes by Chi-square test

† The “Other” race and ethnicity category includes native Hawaiians or Pacific Islanders, multiracial, and other unspecified race and ethnicity.

‡ Participants with missing data on diabetes type and insulin use were excluded.

SOURCE: Behavioral Risk Factor Surveillance System 2022

TABLE 2.

Prevalence of Depression Among Adults Age ≥20 Years, by Diabetes Status, U.S., 2017–2020 Q1

| DIAGNOSED DIABETES | | | | | UNDIAGNOSED DIABETES | PREDIABETES | NORMAL GLUCOSE
| All | A1C^†^ | | | | UNDIAGNOSED DIABETES | PREDIABETES | NORMAL GLUCOSE
| All | <7.0% | 7.0%–<8.0% | 8.0%–<9.0% | ≥9.0% | UNDIAGNOSED DIABETES | PREDIABETES | NORMAL GLUCOSE
N | 1,205 | 565 | 259 | 143 | 188 | 353 | 1,723 | 1,049
| Prevalence (Standard Error)
Positive PHQ-9 screen^‡^ | 12.9 (1.5)** | 11.8 (2.9) | 10.9 (3.3) | 8.5 (3.5) | 16.8 (4.0) | 10.3 (2.8) | 6.5 (0.8) | 7.6 (1.1)
Depression severity^§^
Minimal | 58.4 (2.7)* | 58.2 (4.0) | 61.5 (5.0) | 65.1 (9.4) | 55.1 (5.0) | 57.6 (3.9) | 65.1 (2.8) | 65.7 (1.9)
Mild | 23.4 (3.3) | 25.8 (4.9) | 21.8 (4.8) | 22.5 (5.4) | 20.5 (4.7) | 28.0 (3.5) | 25.1 (2.5) | 23.8 (2.2)
Moderate | 12.1 (1.6)* | 10.1 (3.1) | 12.5 (4.4) | 7.1 (4.1) | 16.3 (4.8) | 11.6 (3.6) | 6.7 (1.1) | 7.2 (1.2)
Moderately severe | 3.9 (0.9) | 3.9 (1.6) | 1.7 (0.9) | 2.3 (1.2) | 6.9 (2.1) | 2.6 (1.1) | 2.2 (0.6) | 2.2 (0.7)
Severe | 2.2 (0.6) | 1.9 (0.7) | 2.6 (0.9) | 2.9 (2.1) | 1.2 (0.9) | 0.2 (0.2)* | 0.9 (0.3) | 1.1 (0.4)
| Mean (Standard Error)
PHQ-9 score^¶^
Total | 0.43 (0.02)** | 0.43 (0.03) | 0.37 (0.05) | 0.37 (0.06) | 0.45 (0.05) | 0.37 (0.04) | 0.33 (0.02) | 0.35 (0.01)
Somatic-affective^║^ | 0.58 (0.03)* | 0.57 (0.05) | 0.50 (0.05) | 0.55 (0.07) | 0.67 (0.08) | 0.53 (0.05) | 0.45 (0.02)* | 0.51 (0.02)
Cognitive-affective^#^ | 0.30 (0.02)** | 0.32 (0.03) | 0.27 (0.05) | 0.22 (0.06) | 0.27 (0.04) | 0.25 (0.03) | 0.23 (0.02) | 0.23 (0.01)

Diagnosed diabetes is based on self-report. Undiagnosed diabetes is defined as A1C ≥6.5% or FPG ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or FPG 100–125 mg/dL; normal glucose is defined as A1C <5.7% and FPG <100 mg/dL. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; FPG, fasting plasma glucose; PHQ-9, Patient Health Questionnaire 9-item depression screen.

* p<0.05 compared to normal glucose by Chi-square test

** p<0.01 compared to normal glucose by Chi-square test

† Not all participants with diabetes had an A1C measurement.

‡ Prevalence of PHQ-9 score ≥10

§ Severity of depression symptoms is based on the nine-item Patient Health Questionnaire depression scale (PHQ-9) total score, classified as none/minimal (values 0–4), mild (values 5–9), moderate (values 10–14), moderately severe (values 15-19), and severe (values 20–27).

¶ Range of values for mean is 0–3 (0=not at all, 1=several days, 2=more than half the days, 3=nearly every day in the past 2 weeks)

║ Somatic-affective score includes items on sleep, fatigability, appetite, and psychomotor agitations/retardation.

# Cognitive-affective score includes items on lack of interest, depressed mood, negative feeling about self, concentration problems, and suicidal ideation.

SOURCE: National Health and Nutrition Examination Surveys 2017–2020 Q1

TABLE 3.

Factors Associated With Prevalence of Self-Reported Depressive Disorder in Adults Age ≥18 Years With Diabetes, U.S., 2022

CHARACTERISTICS | ODDS RATIO (95% CI) | ADJUSTED ODDS RATIO (95% CI)^†^
Age (years)
18–34 | 3.21 (2.53–4.07)*** | 4.83 (2.68–8.71)***
35–49 | 2.10 (1.79–2.46)*** | 2.94 (1.87–4.62)***
50–64 | 1.60 (1.46–1.74)*** | 2.05 (1.55–2.72)***
≥65 (reference) | 1 (ref) | 1 (ref)
Sex
Men (reference) | 1 (ref) | 1 (ref)
Women | 2.00 (1.84–2.18)*** | 1.85 (1.50–2.27)**
Race and ethnicity
Non-Hispanic White (reference) | 1 (ref) | 1 (ref)
Non-Hispanic Black | 0.74 (0.65–0.84)*** | 0.61 (0.45–0.82)**
Hispanic | 0.78 (0.68–0.89)*** | 1.19 (0.68–2.07)
Non-Hispanic Asian | 0.39 (0.27–0.56)*** | 1.94 (0.71–5.26)
Non-Hispanic American Indian/ Alaska Native | 0.87 (0.64–1.18) | 0.38 (0.18–0.80)*
Other^‡^ | 1.62 (1.28–2.05)*** | 1.01 (0.55–1.85)
Type of diabetes
Type 1 | 1.27 (1.00–1.60)* | 1.03 (0.74–1.44)
Type 2 (reference) | 1 (ref) | 1 (ref)
Household income
<$50,000 | 2.18 (1.61–2.95)*** | 0.56 (0.30–1.03)
$50,000 to <$100,000 | 1.39 (1.02–1.89)* | 0.49 (0.27–0.91)*
$100,000 to <$200,000 | 1.39 (1.00–1.93) | 0.60 (0.32–1.12)
≥$200,000 (reference) | 1 (ref) | 1 (ref)
Education
<High school | 1.16 (1.02–1.32)* | 0.85 (0.56–1.31)
≥High school (reference) | 1 (ref) | 1 (ref)
Employment
Employed | 0.96 (0.87–1.05) | 0.71 (0.55–0.93)*
Not employed (reference) | 1 (ref) | 1 (ref)
Marital status
Married | 0.55 (0.51–0.60)*** | 0.73 (0.59–0.91)**
Not married (reference) | 1 (ref) | 1 (ref)
Current health status
Very good/Excellent | 0.28 (0.25–0.32)*** | 0.52 (0.39–0.68)***
Good | 0.45 (0.41–0.50)*** | 0.60 (0.48–0.75)***
Fair/Poor (reference) | 1 (ref) | 1 (ref)
Obesity status^§^
Underweight | 1.05 (0.66–1.68) | 1.75 (0.70–4.34)
Normal weight | 0.68 (0.59–0.78)*** | 0.91 (0.66–1.27)
Overweight | 0.64 (0.58–0.70)*** | 0.76 (0.61–0.96)*
Obese (reference) | 1 (ref) | 1 (ref)
Smoking status
Current smoker | 2.65 (2.35–2.99)*** | 1.69 (1.27–2.26)***
Former smoker | 1.32 (1.20–1.44)*** | 1.35 (1.08–1.70)**
Nonsmoker (reference) | 1 (ref) | 1 (ref)
Insulin use^║^
Insulin use | 1.26 (1.08–1.47)** | N/A
No insulin use (reference) | 1 (ref) | N/A
Chronic health conditions
Yes | 2.29 (2.10–2.49)*** | 1.69 (1.36–2.10)***
No (reference) | 1 (ref) | 1 (ref)

All data are self-reported. CI, confidence interval; N/A, not applicable.

* Statistically significant at p<0.05 compared to the reference group

** Statistically significant at p<0.01 compared to the reference group

*** Statistically significant at p<0.001 compared to the reference group

† Dependent variable: major depressive disorder—yes versus no. Adjusted for independent variables: sex, race, age, type of diabetes, household income, education, employment, marital status, health status, obesity status, smoking status, presence of chronic health conditions.

‡ The “Other” race and ethnicity category includes native Hawaiians or Pacific Islanders, multiracial, and other unspecified race and ethnicity.

§ Defined by body mass index (BMI, kg/m^2^). Underweight: <18.5 kg/m^2^; normal weight: 18.5–24.9 kg/m^2^; overweight: 25.0–29.9 kg/m^2^; obese: ≥30 kg/m^2^.

║ Insulin use was excluded from adjusted regression, as it only includes those with type 2 diabetes.

SOURCE: Behavioral Risk Factor Surveillance System 2022

TABLE 4.

Prevalence of Anxiety Among Adults Age ≥18 Years, by Diabetes Status, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | N | Percent (SE) | N | Percent (SE)
Total | 2,941 | 20.4 (0.8)*** | 24,628 | 17.5 (0.3)
Age (years)
18–34 | 73 | 36.0 (6.1)* | 5,663 | 21.8 (0.6)
35–49 | 309 | 30.7 (3.0)*** | 5,838 | 18.9 (0.6)
50–64 | 937 | 22.4 (1.5)*** | 5,950 | 14.6 (0.6)
≥65 | 1,618 | 14.4 (1.0)* | 7,120 | 12.1 (0.5)
Sex
Men | 1,406 | 15.6 (1.1)** | 11,149 | 12.3 (0.4)
Women | 1,535 | 25.3 (1.3)* | 13,476 | 22.3 (0.5)
Race and ethnicity
Non-Hispanic White | 1,840 | 23.4 (1.1)* | 16,349 | 20.8 (0.4)
Non-Hispanic Black | 478 | 18.0 (2.0)** | 2,623 | 12.0 (0.7)
Hispanic | 399 | 17.9 (2.1)** | 3,535 | 11.6 (0.6)
Non-Hispanic Asian | 157 | 4.4 (1.6) | 1,498 | 7.1 (0.8)
Non-Hispanic American Indian/ Alaska Native | 32 | 34.9 (9.1) | 154 | 27.7 (4.2)
Other^†^ | 35 | 16.7 (7.5) | 469 | 21.9 (2.1)
Lifetime diagnosis of depression^‡^
Diagnosis of depression | 758 | 62.2 (2.0)* | 4,420 | 66.9 (0.8)
No diagnosis of depression | 2,183 | 6.0 (0.6) | 20,208 | 7.0 (0.2)
Severity of depression symptoms^§^
None/minimal | 1,999 | 9.8 (0.7) | 19,277 | 10.2 (0.3)
Mild | 526 | 33.7 (2.3) | 3,199 | 37.9 (1.0)
Moderate | 198 | 55.5 (4.5) | 988 | 56.4 (1.9)
Severe | 138 | 67.3 (4.6) | 613 | 70.3 (2.2)

All data are self-reported. Prevalence of anxiety was assessed by the question “Have you ever been told by a doctor or other health professional that you had any type of anxiety disorder?” SE, standard error.

* p<0.05 compared to no diabetes by Chi-square test

** p<0.01 compared to no diabetes by Chi-square test

*** p<0.001 compared to no diabetes by Chi-square test

† The “Other” race and ethnicity category is defined as other single or multiple races.

‡ Lifetime diagnosis of depression was assessed by the question “Have you EVER been told by a doctor or other health professional that you had any type of depression?”

§ Severity of depression symptoms is based on the eight-item Patient Health Questionnaire depression scale (PHQ-8) total score, classified as none/minimal (values 0–4), mild (values 5–9), moderate (values 10–19), and severe (values ≥20).

SOURCE: National Health Interview Survey 2022

TABLE 5.

Prevalence Rates, Mortality Rates, and Age of Onset for Anorexia Nervosa, Bulimia Nervosa, Any Eating Disorder, and Disordered Eating Behaviors

| ANOREXIA NERVOSA | | BULIMIA NERVOSA | | ANY EATING DISORDER | | DISORDERED EATING BEHAVIORS
| Males | Females | Males | Females | Males | Females | Males | Females
Prevalence in general population | 0.30% | 0.90% | 0.50% | 1.50% | 1.5%* | 3.8%* | - | -
Prevalence in type 1 diabetes population | - | - | - | - | - | 10% | 15.9% | 37.9%
Median age (IQR) of onset (years) | 19.0 (16.0–22.0) | | 18.0 (14.0–22.0) | | 21.0 (17.0–32.0) | | 20.0 (16.0–27.0)
Mortality rate^†^ | 5.1 | | 1.7 | | - | | 3.3

IQR, interquartile range.

* Population: adolescents

† Weighted mortality rate (deaths/1,000 person-years)

SOURCE: Reference (129), copyright © Springer Nature, reprinted with permission from authors.

TABLE 6.

Studies Included in This Review

YEARS OF DATA COLLECTION (REF.) | PSYCHOSOCIAL OUTCOME | STUDY POPULATION | KEY FINDINGS
Youth
N/A (11) | Depression (CDI 2 Short version) | Adolescents with T1D (n=261) and T2D (n=339); age 10–17 years | Depressive symptoms were higher among adolescents with T2D vs. T1D.
2013–2015 (25) | Depression (PHQ-9) | Adolescents with T1D and T2D (n=530) | In adolescents with T1D, A1C levels were higher in high and moderate, compared to low, risk depression risk groups.
2016–2017 (26) | Depression (PHQ-9) | Adolescents with T1D (n=156) and T2D (n=55); age 12–19 years | Clinically significant depressive symptoms were associated with higher A1C in youth with T1D.
2016–2018 (28) | Depression (PHQ-9) | Adolescents (n=1,714); age 12–18 years | 27% of adolescents endorsed at least mild depressive symptoms, which was associated with higher A1C levels and greater risk for DKA.
N/A (31) | Depression (PHQ-9) | Adolescents with T1D (n=120); age 13–17 years | 40% of adolescents reported at least mild depressive symptoms; depressive symptoms were associated with poorer sleep quality.
N/A (35) | Depression (CDI) | Adolescents with T1D (n=264); age 14–18 years | Participants who received a resilience intervention did not demonstrate improved A1C.
N/A (54) | Diabetes distress (PAID) | Adolescents with T1D (n=157); age 12–18 years | Diabetes distress was associated with shorter duration of diabetes.
2017–2019 (51) | Diabetes distress (PAID-C/PAID-T) | Adolescents with T1D (n=155); age 10–14 years | 58% of urban Black adolescents with T1D reported clinically significant diabetes distress.
2020–2022 (61) | Diabetes distress (PAID-T) | Adolescents with T1D (n=172); age 13–18 years | A resilience program improved diabetes distress over 12 months compared to usual care.
2010 (84) | Depression (BDI) anxiety disorders, disordered eating | Youth with T1D (n=150); age 11–25 years | More than one-third of youth screened positive for depression, anxiety, and/or disordered eating.
2015–2016 (86) | Fear of self-injection | Saudi Arabian youth with T1D (n=142); age 13–19 years | Fear of self-injection was independently predicted by older age, multiple daily insulin injections, and fewer finger pricks; fear of self-testing was independently predicted by fewer number of finger pricks.
N/A (109) | Anxiety (STAIC) | Youth with T1D (n=90); age 6–16 years | Lower levels of anxiety were observed following T1D summer camp.
N/A (110) | Anxiety (RCMAS) | Youth with T1D (n=6); age 13–18 | Some youth showed improvements in anxiety following CBT.
2003–2004 (111) | Diabetes-related anxiety (DWS) | Youth with T1D (n=200); age 7–18 years | CGM did not decrease diabetes-related anxiety.
Recruited 1998–2001, followed for 14 years (141) | Eating disorders (cEDE/EDE) | Girls/women with T1D (n=126); age 9–13 years | Probability of developing disordered eating behavior was estimated to be 79%; the probability of developing an eating disorder was 60% by age 25 years.
Adults
2010–2012 (10) | Depression (PHQ-8) | Adults with T1D (n=2,744); mean age 42 years | Longitudinal study of registry participants indicated persistence of depressive symptoms.
2011–2012 (14) | Suicide attempts | Adults with T2D (n=145); age 18–75 years | 9.7% of sample had a history of a suicide attempt.
2014–2020 (27) | Depression (diagnosis code in medical record) | U.S. adults with diabetes (n=813,538); age ≥18 years | People with depression and T1D or T2D were at higher risk for DKA.
2012–2017 (33) | Depression (BDI-II) | Adults with T2D (n=140); mean (SD) age 56 (10.7) years | Participants who received CBT + exercise intervention demonstrated improved A1C.
N/A (52) | Diabetes distress (DDS) | Adults with T2D (n=193); age 25–82 years | Greater increase in regimen and physician distress among White compared with Black participants over 6 months.
N/A (53) | Diabetes distress (DDS) | Older adults with T2D (n=148); age ≥65 years | Black/African American participants reported higher levels of diabetes distress than White participants.
2019–2023 (60) | Diabetes distress (DDS) | Adults with T1D (n=276); age ≥19 years | Emotion-focused and diabetes education programs improved diabetes distress.
2012–2013 (74) | Anxiety disorder, specific phobias | U.S. adults (n=36,138); age ≥18 years | Adults with diabetes have higher prevalence of anxiety disorders and specific phobias.
2022 (78) | Fear of hypoglycemia among adults with T1D | Adults with T1D (n=553); age ≥18 years | Higher fear of hypoglycemia (prevalence 30%) was associated with higher A1C and more comorbidities.
N/A (79) | Fear of hypoglycemia | Dutch adults with T2D (n=1,530); average age 61±11 years | Fear of hypoglycemia was seen in 26% of patients.
N/A (80) | Fear of hypoglycemia | Parents (n=71) of children with T1D age 2–6 years | Fear of hypoglycemia can impact parents and caregivers of children with T1D.
2019–2021 (108) | Fear of hypoglycemia | Young adults with T1D (n=50); age 18–35 years | CBT intervention reduced fear of hypoglycemia.
N/A (81) | Fear of self-injection and self-testing | Dutch adults with diabetes (n=1,275) | Extrapolated population rate from self-report measures and behavioral tests
N/A (83) | Diabetes distress (PAID); well-being | Dutch adults with diabetes (n=1,275); average age 49.7±15.8 years | Fear of self-injection of insulin was associated with below target glycemic management and well-being.
N/A (89) | Anxiety (GAD-7), big five personality | Malaysian women with diabetes (n=141); median age 64.0 years (IQR 52.5–71.0 years) | Neuroticism was associated with diabetes self-management.
N/A (72) | Impaired awareness of hypoglycemia | Adults with T1D (n=2,074); age ≥18 years | Despite use of diabetes technologies, adults with T1D continue to experience impaired awareness of hypoglycemia.
N/A (90) | Anxiety (STAI) | White European and South Asian adults without previous T2D diagnosis (n=6,041); age 40–75 years | No association between anxiety and A1C at screening for T2D
2007 (91) | Anxiety and depression | Adults (n=606; 37% with diabetes) | Symptoms of anxiety and depression were not influenced by diabetes.
N/A (92) | Anxiety and depression (DASS) | Black adults with T2D (n=42); age ≥18 years | Anxiety was associated with A1C but not self-management behaviors.
1999–2009 (95) | Anxiety (PRIME-MD) | Adults initially without diabetes (n=2,156); age ≥60 years | Positive screen for anxiety was associated with diabetes onset.
2000–2012 (100) | Anxiety (STAI) and anger (STA) | Adults initially without diabetes (n=5,598); age 45–84 years | Trait anger was associated with diabetes onset, but trait anxiety was not.
N/A (101) | Stress management | Adults with T2D (n=190); age ≥30 years | Stress management training was associated with small A1C reduction.
N/A (102) | Anxiety (PROMIS), depression (PHQ-8), diabetes distress (PAID) | Latino adults with T2D (n=107); age ≥18 years | Stress management was associated with improvements in depression and anxiety but not A1C or diabetes distress.
2014–2016 (106) | Fear of hypoglycemia (HFS-II) | Adults with T1D (n=155); age ≥25 years | Use of CGM did not decrease fear of hypoglycemia.
1997–1998 (122) | Eating disorders (PRIME-MD PHQ) | Adults in primary care (n=3,000); age ≥18 years | Diabetes was associated with increased risk for eating disorders.
N/A (132) | Binge eating (DEPS-R) | Adults with T1D (n=83); age 18–65 years | Binge eating episodes were related to higher postprandial blood glucose levels than non-binge eating meals.
N/A (146) | Disordered eating behaviors (EDE-Q) | Women with T2D (n=10); age ≥18 years | CBT was associated with a reduction in disordered eating behaviors.
N/A (152) | Schizophrenia | Adults (n=2,225); average age 54.0 years | Individuals with schizophrenia have a higher rate of diabetes.
2000–2010 (154) | Schizophrenia | Taiwanese adults with T2D (n=1 million); age ≥20 years | Prevalence of schizophrenia increased among individuals with T2D.
Youth and Adults
2016–2017 (16) | Suicide risk (PHQ-9 item) | Adolescents and young adults with T1D (n=550); age 10–24 years | 9% of the sample endorsed suicidal ideation.
N/A (17) | Suicide risk (PHQ-9 item and C-SSRS) | Adolescents and young adults with T1D (n=133); average age 19.6±1.1 years | 9.8% reported suicide risk on the PHQ-9; 11.3% reported risk on the C-SSRS.
2016–2017 (18) | Depression and suicide risk (PHQ-9 and PHQ-2) | Adolescents and young adults with T1D (n=2,138); age 12–24 years | Six clinical sites found 10% of those screened reported at least moderate depressive symptoms; 7% endorsed suicidal ideation.
2017–2018 (9) | Depression and suicide risk (PHQ-9 and PHQ-2) | Adolescents and young adults with T1D (n=1,009); age 12–21 years | 7.6% of patients screened positive for at-risk depressive symptoms on the PHQ-2 and 6.7% screened positive on the PHQ-9; 3.1% of patients endorsed suicidal ideation.
2014–2020 (134) | Eating disorders (used service claims) | Adolescents and young adults with T1D (n=168); age 10–39 years | People with T1D and eating disorders were at higher risk for DKA and death.
N/A (125) | Disordered eating behaviors (DEPS-R) | Youth and young adults with T1D (n=2,156) and T2D (n=149); age 10–25 years | Disordered eating behaviors were reported by 21.2% of participants with T1D and 50.3% of participants with T2D.

A1C, glycated hemoglobin; BDI, Beck Depression Inventory; CBT, cognitive behavioral therapy or treatment; CDI, Children’s Depression Inventory; CGM, continuous glucose monitoring; C-SSRS, Columbia Suicide Severity Rating Scale; DASS, Depression and Anxiety Stress Scale; DDS, Diabetes Distress Scale; DEPS-R, Diabetes Eating Problem Survey–Revised; DKA, diabetic ketoacidosis; DWS, Diabetes Worry Scale; (c)EDE-Q, (Children’s) Eating Disorder Examination Questionnaire; GAD-7, Generalized Anxiety Disorder Assessment; HFS, Hypoglycemic Fear Survey; IQR, interquartile range; N/A, not available; PAID(-C/T), Problem Areas in Diabetes(-Children/Teens); PHQ, Patient Health Questionnaire; PRIME-MD, Primary Care Evaluation of Mental Disorders; PROMIS, Patient-Reported Outcomes Measurement Information System; RCMAS, Revised Children’s Manifest Anxiety Scale; SD, standard deviation; STA, Spielberger Trait Anger; STAI, Spielberger State Trait Anxiety Inventory; STAIC, State-Trait Anxiety Inventory for Children; T1D, type 1 diabetes; T2D, type 2 diabetes.

SOURCE: References are listed within the table.