# Prevention of Type 2 Diabetes in Adults

## Summary

Type 2 diabetes is a progressive condition that can lead to multiple organ damage, disability, and premature death. Prediabetes, a high-risk state marked by elevated blood glucose levels below the diagnostic threshold for type 2 diabetes, currently affects 98 million U.S. adults. Individual-level interventions, including intensive lifestyle programs and select medications, have proven effective in delaying or preventing the progression from prediabetes to type 2 diabetes. Landmark clinical trials in the 1990s established the efficacy of these treatment approaches, with lifestyle changes demonstrating greater benefits than medications such as metformin, alpha-glucosidase inhibitors, or lipase inhibitors and more favorable safety than thiazolidinediones. These findings catalyzed translational research to enhance the feasibility, acceptability, and sustainability of delivering intensive lifestyle interventions in real-world settings. Adapted interventions remained effective and were found cost-effective, contributing to policies that established the U.S. National Diabetes Prevention Program (NDPP) and reimbursement from public and private payors.

The NDPP now exists to expand access to evidence-based lifestyle intervention programs nationwide and has reached nearly 819,000 adults through a nationwide network of almost 1,400 community-based organizations and healthcare partnerships. The Centers for Medicare and Medicaid Services leveraged the NDPP infrastructure to offer Diabetes Prevention Program (DPP)-like intervention services as a covered health benefit for high-risk Medicare beneficiaries. However, despite these remarkable examples of translating research into policy and practice, only a small proportion of U.S. adults living with prediabetes today are aware they are at high risk for type 2 diabetes, and far fewer have knowledge of or have taken part in a DPP-like intervention program. Emerging research highlights the need for innovative strategies to improve engagement, including leveraging technology and tailoring interventions to diverse social and cultural contexts. Although multiple medications have efficacy in type 2 diabetes prevention, none have received U.S. Food and Drug Administration approval for this indication, and many expert groups recommend their use only when lifestyle interventions are ineffective or unavailable; subsequent utilization remains low and health payor coverage is limited. While new medications, such as glucagon-like peptide-1 (GLP-1) receptor agonists, show promise for type 2 diabetes prevention, their long-term impacts and use in real-world clinical settings remain under investigation.

This article presents a narrative scoping review of the extremely active area of type 2 diabetes prevention science during the last three decades. We focus on the U.S. experience and in areas where research to date has been the strongest, namely individual-level intensive lifestyle interventions and select medications that have been studied rigorously. We include a focused evidence review of seminal efficacy trials, as well as the translational research that advanced the implementation and dissemination of intensive lifestyle interventions into the health care and population health sectors. Finally, we review the current state of U.S. diabetes prevention policy and practice, and we conclude with prevailing challenges, unanswered questions, and areas needing further research and action.

## Introduction

### Overview of the Goals and Outline for This Article

The overarching aim of this review is to appraise and synthesize the evidence base for individual-level interventions considered safe and effective for the primary prevention of type 2 diabetes. We focus on where the evidence to date for type 2 diabetes primary prevention has been the strongest, primarily involving lifestyle and pharmacological interventions targeting high-risk adults. In the following sections, we review efficacy trials designed to evaluate and compare different interventions with respect to the outcome of progression to type 2 diabetes, followed by an overview of translational research that advanced the implementation and dissemination of intensive lifestyle interventions into the health care and population health sectors, focusing on the U.S. experience. Finally, we review the current state of U.S. diabetes prevention policy and practice, and we conclude with prevailing challenges, unanswered questions, and areas needing further research and action. This article updates the Diabetes in America, 3rd edition chapter Prevention of Type 2 Diabetes (1).

Type 2 diabetes mellitus is a chronic and progressive health condition resulting from a disruption of the normal actions of insulin to enable cells throughout the body to take up and store nutrients, including glucose, fatty acids, and amino acids. As glucose reaches high concentrations in blood and extracellular fluid, it causes oxidative damage to tissues, such as peripheral nerves, the retina, vascular endothelium, and renal glomerulus. This damage leads to permanent physiological impairments that can worsen over months to years before the emergence of any symptoms. In this context, prompt identification and treatment of type 2 diabetes are critical. As a result of population growth and advances in practice, the number of U.S. residents diagnosed and treated for type 2 diabetes has increased more than fivefold since 1980 (2,3), imposing a tremendous toll on individuals, families, health systems, and society. Without parallel efforts to prevent type 2 diabetes, this toll will only continue to rise.

This article focuses on preventing the most common phenotype of type 2 diabetes, which often presents in middle-aged adults with overweight or obesity. Research has described less common phenotypes of type 2 diabetes, including ketosis-prone, maturity-onset diabetes of the young, and latent autoimmune diabetes in adults (4,5). Because these phenotypes of type 2 diabetes are not fully understood, and most type 2 diabetes prevention trials did not distinguish progression to these distinct type 2 diabetes phenotypes, their primary prevention is considered beyond the scope of this review. This article also does not review the emerging literature on prevention of type 1 diabetes, given the significant differences in its underlying pathophysiology and treatment approaches (6).

The evidence to date for type 2 diabetes primary prevention has been the strongest in the areas of lifestyle and pharmacological interventions targeting high-risk adults. This article outlines the major goals of type 2 diabetes prevention and the progression of intervention evidence, including clinical trials demonstrating efficacy and safety, followed by translational research investigating an array of implementation strategies to increase adoption, reach, and population effectiveness, including implications for individuals and groups that are at high risk but have proved challenging to reach or appear to benefit less from current implementation strategies. Finally, we summarize gaps in the literature and implications for future research and policy. Comprehending the evidence base for type 2 diabetes primary prevention will benefit first from a short overview of nutrient metabolism with and without normal insulin action, what it means to develop type 2 diabetes, both biologically and clinically, and how individuals can be identified in the months to years prior to a type 2 diabetes diagnosis, when primary prevention is still achievable.

### Nutrient Metabolism With and Without Normal Insulin Action

Glucose is a dominant energy substrate for normal cellular reproduction, growth, and repair. To fuel these processes, glucose must be delivered and transported into each cell or produced directly by it. Most cells have an intrinsic ability to produce glucose “endogenously” from cytosolic stores of glycogen (large carbohydrate molecules synthesized by cells to store excess glucose efficiently), as well as from lipids (fats) or even amino acids, but most human cells do not produce enough glucose to meet their own energy needs. Liver cells (hepatocytes) produce large amounts of glucose and release it into circulation, serving as the primary source of blood glucose in the absence of a recent meal. Liver and other cells carry out endogenous glucose production nearly continuously, unless stimulated to stop by the hormone insulin.

After digestion of a meal, pancreatic β-cells respond to the rapid rise in blood glucose and other nutrients by secreting insulin into circulation. Insulin binds to surface receptors on cells throughout the body and triggers a cascade of intracellular signals that slow down endogenous glucose production and increase the uptake and storage of glucose and other nutrients present in the extracellular fluid. Muscle cells (myocytes) respond to insulin by taking up and storing large amounts of glucose as the blood concentration rises sharply after a meal (7). Liver cells respond to insulin by reducing endogenous glucose production and, instead, taking up glucose to produce glycogen (which is stored) and fatty acids (which are stored or exported into circulation as lipoproteins) (8,9). Adipose cells respond to insulin by taking up fatty acids and storing them as lipids (9). Without these normal insulin actions, blood glucose and fatty acid concentrations rise to unnaturally high levels after a meal and fail to return to normal levels even after many hours without eating.

### Development of Type 2 Diabetes

All individuals with type 2 diabetes have acquired defects in both insulin action and secretion. Even when insulin is present, cells are insensitive to its normal effects. This insulin “resistance” begins and typically progresses over months to years before diabetes is diagnosed (10). Pancreatic β-cells compensate by producing additional insulin to overcome this resistance, stimulating cells to remove rather than produce glucose, and restoring blood glucose to normal physiological levels (11). This compensatory response eventually becomes insufficient, resulting in severe and prolonged elevation of blood glucose after a meal. Hepatic glucose production also persists unrestrained, and hepatic glucose uptake and storage become insufficient to return blood glucose back to normal even many hours after a meal. When these deficits become severe enough, glucose levels rise above the thresholds for a diabetes diagnosis.

The American Diabetes Association (ADA) currently defines diabetes based on the results of any one of three different diagnostic tests: plasma glucose after an 8–14-hour overnight fast (i.e., fasting plasma glucose [FPG]) ≥126 mg/dL (≥7.0 mmol/L), plasma glucose measured 2 hours after oral ingestion of a 75 g glucose solution (i.e., 2-hour plasma glucose) ≥200 mg/dL (≥11.1 mmol/L), or glycated hemoglobin (A1C; a test of the level of glycation of the red blood cell protein hemoglobin) ≥6.5% (≥48 mmol/mol) (12).

Management goals for people with blood glucose meeting or exceeding these thresholds focus on monitoring and lowering blood glucose (often with one or more medications), intensifying the medication management of other atherosclerotic disease risk factors, and monitoring and promptly treating microvascular and neuropathic complications (6,13). Individuals who initiate treatment for type 2 diabetes are less likely to suffer acute or long-term complications of persisting hyperglycemia (14), but they also encounter additional cognitive, emotional, and physical burden resulting from diabetes self-management tasks and behaviors and may experience direct harms of treatment (e.g., medication side effects or hypoglycemia). Healthcare use also becomes more frequent, complex, and costly. Adults without diabetes perceive both the complications of type 2 diabetes and the actions needed for its intensive management to represent a profound loss of quality of life (15), and those who have been informed that they are at high risk for progression to type 2 diabetes express willingness to pay hundreds to thousands of dollars to gain access to interventions effective for type 2 diabetes primary prevention (16).

### Historical Clues for Identifying and Modifying Risk for Type 2 Diabetes

Epidemiologic research during the past century showed that family history, middle age, centripetal obesity, physical inactivity, and poverty all are associated with increased risk for developing type 2 diabetes (3). Serial cross-sectional studies showed striking shifts in the population prevalence of diabetes and obesity (2,17), suggesting that something causative was increasing in the environment and driving susceptible individuals to develop type 2 diabetes more often (18) and that obesity was either an intermediate state or parallel outcome of that process. It also was apparent that genes, aging, dietary composition, physical activity, visceral fat accumulation, and environmental conditions were critical to understanding the pathophysiology and prevention of type 2 diabetes.

Observations from the treatment of type 2 diabetes held important clues for its prevention. Low calorie diets have been useful in the clinical management of type 2 diabetes for hundreds of years, improving glucose control and reducing the need for glucose-lowering medications (19). Physical activity not only lowers blood glucose acutely but also amplifies the effects of insulin treatment on blood glucose control for up to 72 hours, suggesting that exercise somehow restores, albeit temporarily, some of the lost sensitivity to insulin (20,21). Finally, weight loss achieved through behavioral changes, medications, and metabolic bariatric surgery has significant effects on insulin sensitivity and secretion, so long as weight loss is maintained (22). Observations such as these, dating back many decades, catalyzed a new era of experimental diabetes prevention research beginning in about the 1990s, which now serves as the foundation for the evidence reviewed by this article.

### Dimensions of Type 2 Diabetes Primary Prevention

Primary prevention refers to actions taken before the onset of a disease to prevent the disease from ever occurring (23). Type 2 diabetes primary prevention involves actions to reduce the numbers of individuals without diabetes today from developing type 2 diabetes in the future. Since biological progression of type 2 diabetes is defined by exceeding specific thresholds for plasma glucose concentration or A1C level, an effective primary prevention strategy might be defined as any approach that prevents or slows the progression of abnormally high blood glucose (10). Mechanistically, this might be interpreted as any strategy with the potential to safely and effectively slow or reverse type 2 diabetes’ underlying metabolic impairments, namely insulin resistance and insufficient insulin secretion (10). However, from a purely biological perspective, there is little difference in the risk for symptoms or for acute or chronic complications between individuals with blood glucose just below versus just above the type 2 diabetes diagnosis threshold. For example, Figure 1 depicts a graded relationship between the proportion of individuals who newly develop microvascular and macrovascular complications over 10 years, based only on increasing levels of their A1C. The relationship reveals no abrupt change or step-up at the diabetes threshold, and similar relationships have been demonstrated with fasting and 2-hour plasma glucose tests. This pattern implies that initiating type 2 diabetes treatment at an A1C level 0.1% higher or lower has very little implication for the risk of either acute or long-term type 2 diabetes complications for an individual patient. What does change, however, is the experience of being given that diagnosis and the incremental burden of its treatment. In this context, the benefits of type 2 diabetes prevention from both an individual and societal level lie more in the opportunity to reduce the emotional, physical, social, and financial burden of the clinical diagnosis and intensive management of type 2 diabetes. The perspective that a preventive intervention not only slows biological progression but also safely avoids or postpones its clinical treatment enables a sharper distinction between the goals of type 2 diabetes treatment (i.e., to reduce the burden of acute and long-term complications) from the goals of its prevention (i.e., to prevent or delay the diagnosis and management of type 2 diabetes).

The framing of a goal to prevent or delay more intensive type 2 diabetes treatment holds additional implications for the consideration of preventive interventions, because most interventions with the potential to slow biological progression to type 2 diabetes also add considerable self-management burden, additional visits with service professionals, additional medication taking, the potential for treatment-related symptoms or side effects, and immediate increases in direct medical costs. Many medications with established efficacy and safety for type 2 diabetes prevention are already used for diabetes treatment, so from the patient and clinician perspective, their use may feel no different from having type 2 diabetes already and treating it. An ideal type 2 diabetes prevention intervention would be effective, rarely harmful, viewed as acceptable or appropriate, less burdensome than treating type 2 diabetes, readily accessible, and affordable. Multiple individual and population-wide intervention strategies have demonstrated strong potential to slow biological progression to type 2 diabetes, but none is curative or ideal for all people. Our article considers the tradeoffs among alternative intervention approaches at both individual and societal levels.

### A Population Problem With No Imminent Population-Wide Solution

The U.S. Centers for Disease Control and Prevention (CDC) estimates that 38.4 million U.S. residents had diabetes in 2020, reflecting a growth from 5.3% of the adult population in 1980 to 11.3% in 2020 (3,24). When the effects of a disease are felt population-wide, it implicates the presence of an environmental or systemic cause, and population-level interventions, such as policy, systems, or environmental changes, typically hold the strongest potential to restore population health (18). When environmental drivers remain incompletely understood, however, or when social, political, or economic barriers prevent efforts to address them, then those who are most susceptible (i.e., the “high risk”) still may benefit from individual-level interventions that prevent or delay the disease, even while they remain living within the environmental conditions that promote the disease.

Although a full appraisal of population-wide interventions to prevent type 2 diabetes is beyond the scope of this article, it is helpful to highlight briefly the importance of such strategies, as well as some of the prevailing challenges that have stimulated a much greater emphasis on interventions that target high-risk individuals. Some potentially beneficial population-wide strategies for type 2 diabetes prevention include policies that mandate removal of trans fats from the food supply (25), changes in urban planning that enable and increase physical activity (26), or economic policies that improve access to healthy foods or make unhealthy foods more costly, such as a sugar-sweetened beverage tax (27,28). Educational and behavioral economic interventions implemented at population levels also can shape decisions and actions that that are upstream of diabetes development, such as restaurant menu labels disclosing the caloric content of foods to improve individuals’ dietary quality (29). Policies or environmental changes could serve to remove or reduce exposures that accelerate progression to type 2 diabetes in ways that are entirely outside of an individual’s control. For example, multiple chemicals used as pesticides, in manufacturing, or in food processing have been associated with diabetes and other metabolic impairments in animal studies (30,31). Poverty also has strong effects on type 2 diabetes progression, and one landmark randomized trial even demonstrated that providing housing vouchers that enabled low-income women and children to move to a lower-poverty neighborhood reduced obesity and incident diabetes over 12 years (32).

Despite the importance and promise of population-wide strategies for type 2 diabetes primary prevention, existing science regarding the environmental causes of type 2 diabetes remains incomplete, and there has been limited public and political will to support or sustain population-wide interventions with strong promise for preventing obesity and type 2 diabetes (25,33,34,35). These barriers currently make the available evidence for population-wide approaches less actionable, and the remainder of our article focuses on evidence for interventions targeting high-risk individuals and how they are being implemented.

### Scope and Limitations of Individual Interventions to Prevent Type 2 Diabetes

Individual-level interventions with efficacy to slow biological progression to type 2 diabetes include surgical, pharmacological, and behavioral interventions that operate through a variety of mechanisms to slow the pathophysiologic progression of insulin resistance or insufficient insulin secretion leading to type 2 diabetes. Surgical procedures bring about anatomic changes that reduce gastric capacity or bypass a portion of the small intestine to reduce appetite, increase satiety, and reduce calorie absorption, all of which produce significant weight loss that improves insulin sensitivity and reduces demand on β-cells to hyper-secrete insulin in order to maintain glucose homeostasis (36,37). These procedures also alter gut hormone signals that have direct effects on increasing insulin secretion even before weight loss ensues (38). Some metabolic medications stimulate acute improvements in insulin secretion or sensitivity while the drug remains bioavailable, and others suppress appetite and increase satiety, leading to lower caloric intake and weight loss sufficient to improve both insulin sensitivity and secretion. Behavioral interventions provide education, behavioral skills training, and recurring motivational, coping, and problem-solving support delivered through professionals (i.e., coaches) or technology to enable and sustain efforts to reduce dietary calories, increase physical activities, and lose weight (39). Physical activity also directly increases skeletal muscle glucose uptake acutely during exercise and stimulates subacute improvements in insulin sensitivity for up to 72 hours afterwards (40).

Weight loss achieved through any of these modalities is associated with reductions in visceral ectopic fat, accompanied by lasting improvements in insulin sensitivity and signaling so long as the weight loss is maintained. Maintaining weight loss is a challenge with all interventions, and weight regain increases sharply when metabolic medications or behavioral intervention support is stopped. There is strong evidence from rigorous, randomized controlled trials that offering interventions with these properties to groups of high-risk individuals without type 2 diabetes, who already have signs of insulin resistance, can reduce the proportion of them who experience future progression to type 2 diabetes.

### Social and Economic Considerations When Putting Prevention Into Practice

When strong evidence supports the efficacy and safety of an individual-level preventive intervention, decisions must be made regarding how best to offer those interventions and whom to target with them in clinical and community practice. If science translated seamlessly into practice, then interventions could be administered exactly as they were in clinical trials, and they would be offered to target populations that mirror the participants of those trials. Many randomized efficacy trials of type 2 diabetes prevention interventions determined eligibility using the oral glucose tolerance test (OGTT) and only randomized participants with elevated 2-hour plasma glucose. Unfortunately, this test is burdensome to perform and rarely used in U.S. clinical practice. In this context, reaching people with evidence-based preventive interventions in real-world settings requires alternative approaches to identify high-risk individuals. Implementing interventions with fidelity to efficacy trials also can be challenging and costly. Among the medications with proven efficacy to prevent type 2 diabetes, none have U.S. Food and Drug Administration (FDA) approval for the indication of type 2 diabetes prevention, many cost from several hundred to several thousand dollars per year to supply, and health insurance coverage for the costs of these medications is limited. Behavioral interventions are challenging for service organizations to administer and also require considerable cost to deliver and sustain (41,42). Efforts to offer these interventions in routine practice often require a departure from the approaches used in efficacy trials to improve their feasibility and sustainability during real-world implementation.

In the United States, the Affordable Care Act (ACA) requires that the costs to offer highly effective preventive interventions be covered by commercial health insurance plans and public insurance programs, such as Medicare and Medicaid. Commercial insurance plans are funded from employer contributions and the payroll deductions collected from all employees, Medicare is funded by payroll deductions and public tax revenues, and Medicaid is funded by state and federal tax revenues. Given the social nature of insurance funding, all of these programs involve a form of social contract among the contributors, with the principle that spending is directed towards interventions that not only are safe and effective but are administered in ways that are fair, affordable, and limit waste (i.e., they are a valuable use of resources). Because nearly 98 million U.S. adults (38%) are considered at high risk for developing type 2 diabetes (3), and individual preventive interventions are costly, insurance spending to make them more accessible can escalate very quickly. This is important, because these forces strongly shape decisions about how evidence-based preventive interventions are offered in clinical practice, which strategies are made more accessible through health insurance reimbursement, and which high-risk individuals are targeted to receive them.

### Prediabetes as a Classification for High-Risk Individuals

There currently is no single test to identify precisely who will develop diabetes in the future and who will not; however, multiple tests are useful clinically in risk stratifying adults for the purposes of providing more targeted support for type 2 diabetes prevention. The ADA recommends classifying adults as high risk for type 2 diabetes (i.e., “prediabetes”) when the result of the FPG test is 100–125 mg/dL (i.e., impaired fasting glucose [IFG]; 5.6–6.9 mmol/L), the 2-hr post-glucose load plasma glucose is 140–199 mg/dL (i.e., impaired glucose tolerance [IGT]; 7.8–11.0 mmol/L), or the A1C is 5.7%–6.4% (39–46 mmol/mol) (12). Fasting and 2-hour plasma glucose tests help to identify one or both of the underlying pathophysiological impairments (i.e., insulin resistance and insufficient β-cell insulin secretion) that underlie and precede progression of blood glucose to exceed the type 2 diabetes threshold (10,43,44). Fasting glucose increases in the presence of hepatic insulin resistance. As hepatic insulin resistance progresses, hepatic glucose production and insufficient hepatic glucose clearance result in higher levels of plasma glucose many hours after the last meal, in addition to increased compensatory insulin secretion by β-cells (i.e., hyperinsulinemia). Elevation of 2-hour plasma glucose increases with impaired glucose uptake by myocytes following a meal (i.e., muscle insulin resistance) and insufficient insulin secretion in response to the meal. Patterns in which plasma glucose concentrations are at the higher end of the population distribution, despite ongoing insulin secretion, reflect either insulin resistance, insufficient β-cell insulin secretion, or both.

Diagnostic tests to assess plasma insulin concentration are rarely performed in routine clinical practice, so plasma glucose tests alone are used to implicate early pathophysiological defects in insulin sensitivity and secretion. Moreover, the OGTT used to assess 2-hour plasma glucose is burdensome to perform in clinical practice and rarely used. Fasting glucose tests require return visits following an overnight fast, which presents an additional barrier to timely test completion. A1C, which yields a similar result when assessed before versus after meals, is the most common and practical diabetes diagnostic test performed in U.S. clinical practice today. A1C reflects average daily blood glucose concentrations over the past 40–70 days (45,46), but it does not differentiate specific patterns of insulin resistance or insufficient insulin secretion as do IFG and IGT. The presence of either IFG or IGT may contribute to average blood glucose and to the A1C level, but only 37% of U.S. adults with A1C 5.7%–6.4% have IFG, and only 31% have IGT (47). Moreover, 61% of adults with prediabetes overall have IFG or IGT but a normal A1C value (i.e., <5.7%) (47). Finally, among U.S. adults who meet any one of the three recommended glycemic definitions for prediabetes, insulin sensitivity is estimated as abnormal for only about 40%–45%, normal for 20%–25%, and “intermediate” for about 30%–35% (48). Thus, the use of these three tests to define prediabetes identifies different high-risk groups with only modest overlap, and together they offer a pragmatic yet imprecise approach to identify high-risk individuals.

In spite of the limitations of testing for prediabetes, IFG, IGT, and elevated A1C all identify groups with increased average probability of progression to future type 2 diabetes. Figure 1 illustrates the 10-year probability of progression to a clinical diabetes diagnosis for groups of individuals with different A1C levels below the diabetes threshold. Although there is a steep gradient towards increasing risk as the A1C result approaches the diabetes threshold, it is notable that about half of individuals with subthreshold A1C results of 6.0%–6.4% (42–46 mmol/mol) do not progress to type 2 diabetes within 10 years. Similar relationships have been demonstrated for both fasting and 2-hour plasma glucose tests. Table 1 summarizes the underlying metabolic defects and average risk of progression to type 2 diabetes associated with groups of individuals who express different phenotypes of prediabetes, as currently defined. These test characteristics have important implications for intervention effectiveness in the real world. Strategies that involve only one form of high-risk testing, such as the A1C, will misclassify more than half of high-risk adults (i.e., those with only IFG or IGT) as normoglycemic, potentially missing an important opportunity for primary prevention. Moreover, if one-half or more of the individuals who are classified as high risk have relatively normal insulin sensitivity and secretion, then intensive and relatively costly diabetes prevention interventions may be offered to many people who are at generally lower risk for progression to type 2 diabetes in the near future.

Our article critically reviews what is known about the effectiveness of targeting individuals with prediabetes for real-world delivery of diabetes prevention interventions, as well as opportunities for future research.

## Data Sources and Limitations

A scoping review is a systematic form of information and literature synthesis that identifies key concepts, maps and summarizes the landscape of existing research, and uncovers existing knowledge gaps for a specific topic. Our narrative scoping review focuses on type 2 diabetes prevention for adult populations, and most of the studies that are included targeted high-risk populations defined by risk characteristics and blood tests indicating IFG, IGT, or elevated A1C in the “prediabetes” range. We began with the goal of including and updating primary research that was reviewed by the Diabetes in America, 3rd edition chapter Prevention of Type 2 Diabetes (1). We updated prediabetes and diabetes statistics using the CDC’s National Diabetes Statistics Report and other national surveillance systems, and we used PubMed and other National Library of Medicine databases to identify other recent narrative and systematic reviews related to this topic, as well as new primary research reports published since the last update was written.

Our synthesis of intervention efficacy and effectiveness focused on reports of primary studies with randomized and quasi-randomized comparative designs. Our synthesis of evidence for translation and implementation strategies focused on a broader range of study designs using experimental, natural experimental, or mixed-method approaches. All authors collaborated to make decisions regarding the inclusion or exclusion of individual research reports using a consensus approach. One of us (RTA) reviewed and updated data from research included in the prior (3rd edition) report, and two reviewers (RTA and MJO) reviewed, abstracted data, and synthesized findings from newly identified efficacy and effectiveness trials. Because of the focused nature of the scoping review method, it is possible that some relevant research reports were omitted from our synthesis. Figures and tables integrate data from multiple sources (as is indicated in footnotes) to generate new data or visualizations of data to illustrate key principles or summary information about the current state of type 2 diabetes primary prevention research. The discussion of implications of past research and U.S. implementation strategies, as well as opportunities for further research are solely the perspectives of the authors.

## Defining What Works: Major Efficacy Trials of Type 2 Diabetes Prevention

### Clinical Trials of Intensive Lifestyle Interventions for Type 2 Diabetes Prevention

Efficacy trials are critical for demonstrating that an intervention is safe and can improve a desired outcome, such as slowing progression of abnormal glucose metabolism to reduce development of type 2 diabetes. By design, efficacy trials often recruit individuals who not only are eligible members of the target population but also are motivated and able to adhere to the research protocol and accept random assignment to different possible interventions. Landmark efficacy trials were designed to evaluate and compare the effects of medications and lifestyle interventions on progression of blood glucose above the type 2 diabetes threshold, under optimal conditions of participant adherence and intervention fidelity. From 1997 to 2002, three large, randomized trials demonstrated that intensive lifestyle interventions can prevent or delay the progression of blood glucose above the type 2 diabetes diagnosis threshold for adults with blood glucose in the prediabetes range. The glycemic eligibility criteria for each of these landmark efficacy trials and subsequent trials can be found in Table 2. The Chinese Da Qing Study (1997), Finnish Diabetes Prevention Study (2001), and the U.S. Diabetes Prevention Program (DPP) (2002) each independently demonstrated that structured lifestyle interventions focused on healthy eating, physical activity, and modest weight loss reduced the incidence of type 2 diabetes by 42%–58% (49,50,51).

Participants who developed diabetes in these primary prevention trials were reenrolled into long-term follow-up studies to evaluate the durability of treatment effects and whether those primary effects impacted long-term secondary outcomes, such as microvascular or macrovascular complications. To date, these studies have not demonstrated whether interventions that successfully prevent or delay type 2 diabetes also have significant effects on long-term complications (52,53,54,55), but this is somewhat unsurprising for three reasons. First, these trials were not designed to evaluate differences in long-term complications, so the limited sample sizes of participants and their relatively low baseline risk for complications limit statistical power for detection of meaningful differences in new complications. Second, after the primary outcome of incident diabetes was analyzed, these trials either reduced the intensity of intervention support for the active treatment arm, offered some version of active treatment to participants initially randomized to the control arm, or both. These protocol changes attenuate the ongoing differences in treatment between the study arms and reduce the likelihood that more distal outcomes will be different. Third, unlike in clinical practice, where the diagnosis and intensive treatment of type 2 diabetes may be delayed for months to years after its biochemical onset, the procedures for frequent follow-up testing used in all prevention trials served to identify incident diabetes and encourage prompt treatment for participants in all study arms. Since intensive treatment is known to have powerful effects on reducing diabetes complications (14), participants in all arms of the prevention trials received access to services that kept complication rates comparably low, regardless of their initial treatment assignment. As such, it is unlikely that primary prevention trials with these characteristics would demonstrate differences in long-term complications, and we rely on this evidence primarily to underscore that preventive interventions delay the biochemical progression to diabetes, that periodic surveillance through serial retesting for diabetes serves to minimize the time any individual is exposed to undiagnosed diabetes, and that prompt intensive treatment after a type 2 diabetes diagnosis serves to minimize the burden of complications over the remaining life course.

Published findings of these and other randomized efficacy trials with primary prevention of type 2 diabetes as a principal or prespecified secondary outcome are summarized in Table 2.

### Core Components and Mechanisms Underlying Intensive Lifestyle Interventions

Post-hoc studies of the lifestyle intervention efficacy trials demonstrated that weight loss was the dominant predictor of diabetes prevention; in the DPP, every 1 kg of additional weight loss by lifestyle intervention participants translated to a 16% lower average risk of type 2 diabetes (49,50,56). The trial interventions adopted many common strategies for supporting healthy behavior change and weight loss, including recurring contact with trained professionals to support goal setting, stimulus control, self-monitoring, and problem solving related to dietary intake and levels of physical activity (49,57,58). The DPP supported participants to set a weight loss goal of 7% or greater decrease in their initial body weight over 4–6 months (i.e., equating to a pace of about 0.5–1 pound [0.25 kg–0.5 kg] per week), by performing 150 minutes per week of moderate or vigorous physical activity, as well as achieving individually tailored goals for daily intake of total calories and fat grams (57). Contact with intervention professionals was frequent and ongoing, albeit at tapering intensity—defined by the number and length of in-person sessions—until a participant developed type 2 diabetes or the trial ended; across all three trials, the average duration of intervention support spanned 2.8 to 6 years (49,50,51). The consistency of intervention strategies and durability of the treatment effects observed across these trials that enrolled diverse cohorts on three continents established intensive lifestyle interventions as a powerful, evidence-based treatment for diabetes prevention.

### Research to Inform Implementation

Though efficacy trials of intensive lifestyle interventions catalyzed enthusiasm over the potential to halve the population rate of incident type 2 diabetes, tremendous barriers to implementing those interventions in real-world settings persist today. Intensive lifestyle interventions provide recurring contact with a behavior coach to support goal setting, self-monitoring and regulation of diet and activity behaviors, skill building, problem solving, and emotional support as participants attempt to lose and maintain weight while remaining in physical and social environments that often make healthy behaviors difficult (39). In this context, coaching support offered in most efficacy trials was frequent and continuous. This approach demands a high level of capacity from delivery organizations and is costly.

Implementation strategies are methods or actions designed to overcome implementation barriers, increase the pace, effectiveness, and scale of implementation, and sustain interventions over time (59,60). Stemming from the earliest efficacy trials for type 2 diabetes prevention 25 years ago, research has increased exponentially on strategies to adapt, implement, and sustain efficacy-proven lifestyle interventions. The goals of these translational research efforts are to preserve intervention fidelity and effectiveness, while reaching more people at a cost that is more financially sustainable for delivery organizations and third-party payors. Additional research has focused on identifying gaps and barriers in the implementation of medication interventions for diabetes prevention and effective strategies for improving their adoption and reach. A narrative review of the lessons learned from this implementation research, as well as important prevailing challenges and areas where there is need for further research to guide policy and practice, can be found in the Research to Translate Clinical Trial Interventions Into Real-World Practice and Population Health section.

### The Evidence Base for Physical Activity

Clinical studies show meaningful improvements in insulin sensitivity for 24–72 hours following many different forms of physical activity and across wide ranges of activity duration and intensity (20,21,61). It is likely that increases in physical activity supported by landmark intensive lifestyle interventions have direct effects on primary prevention of type 2 diabetes (62), as well as indirect effects resulting from improved weight loss or weight loss maintenance. In the Da Qing Study, interventions promoting diet alone (31% reduced risk), exercise alone (46% reduced risk), and both diet and exercise (42% reduced risk) were all effective at reducing risk of diabetes (49). Post-hoc analyses of the DPP and Finnish Diabetes Prevention Study also provide evidence of the importance of physical activity independent of weight loss. In the DPP, among lifestyle intervention arm participants who did not meet weight loss goals in the first year, those who achieved the physical activity goal experienced a relative risk reduction for type 2 diabetes that was still 44% lower than those who did not reach the goal (56). Similarly, individuals in the Finnish Diabetes Prevention Study who increased their moderate-to-vigorous or strenuous physical activity the most were 49% less likely to develop diabetes than those whose physical activity decreased or did not change, even after adjustment for diet and body weight changes during the study (63). Though most lifestyle interventions have included a focus on increased aerobic activity, additional research has found that supervised aerobic training, resistance training, and combined aerobic and resistance training in conjunction with dietary intervention can each achieve meaningful reductions in the risk of diabetes compared with control (64).

### The Evidence Base for Nutrition

A wide array of nutritional strategies that result in reduced calorie consumption support successful weight loss (65), but it remains unclear whether specific eating patterns or macronutrient compositions have superior effects on slowing progression to diabetes, independent of their role in achieving weight loss goals. Many popular dietary approaches for weight loss, including the ketogenic diet and other “fad” diets discussed commonly in the media and nonscientific literature, have not been rigorously studied for type 2 diabetes prevention. The dietary intervention in the DPP focused on reduction of total dietary fat and calories (66), but other dietary patterns may also be beneficial for diabetes prevention or improving glycemic control in people with prediabetes. Both low-fat and Mediterranean-style eating plans have strong evidence from clinical trials for prevention of diabetes (6,49,50,51,67,68,69,70). Additional trials suggest beneficial effects on glucose levels or glucose metabolism following low-carbohydrate, high-protein, and plant-based dietary patterns (69,70,71,72,73,74,75).

In these contexts, there is insufficient evidence today to recommend a specific dietary approach, eating pattern, or macronutrient composition for type 2 diabetes prevention (6,70). Consistent with the evidence base for intensive lifestyle interventions, nutritional approaches should focus on ensuring dietary modifications are culturally appropriate, feasible, and sustainable within a participant’s life context and should be revisited and tailored to achieve weight goals that are about 5%–10% below baseline body weight, over a time period of about 16–26 weeks, which yields an average pace of about 0.5–2 pounds (0.2–0.9 kg) of weight loss per week (66,76,77).

## Pharmacological and Surgical Interventions

### Clinical Trials of Metformin for Type 2 Diabetes Prevention

Multiple randomized trials have investigated the efficacy and safety of medications for the primary prevention of type 2 diabetes, and the strongest evidence supports the use of metformin (Table 2). This medication in the biguanide class inhibits gluconeogenesis in the liver and has secondary effects on decreasing intestinal glucose absorption and increasing insulin sensitivity (78).

The DPP included an arm that was randomly assigned to take metformin 850 mg twice daily. In this study (79), participants randomized to the metformin arm lost 2.1 kg and experienced a corresponding 31% reduction in diabetes incidence during 2.8 years of follow-up (51). The following demographic groups experienced a greater diabetes risk reduction from metformin: younger adults age 25–44 years (44%) and middle-aged adults age 45–59 years (31%), Black participants (44%), women with histories of gestational diabetes (50%), and those with fasting glucose 110–125 mg/dL (48%) or a body mass index (BMI) ≥35 kg/m^2^ (53%) (6,51,80). The efficacy of metformin for reducing type 2 diabetes incidence was not statistically significant among adults age ≥60 years (11%, 95% CI -33% to 41%) (51). ADA practice guidelines for type 2 diabetes prevention recommend considering metformin use for adults with prediabetes with a history of gestational diabetes, those age 25–59 years with BMI ≥35 kg/m^2^, and those with FPG ≥110 mg/dL or A1C ≥6.0% (6).

A short-term study was conducted to determine the effect of temporarily stopping metformin on type 2 diabetes incidence, which is discussed in-depth in the Disentangling Glucose-Lowering Effects Alone From Primary Prevention section. Long-term follow-up of DPP participants after the initial trial period demonstrated that relative risk reductions observed for participants randomized to the metformin arm diminished over time but remained 18% lower than placebo controls over 10–15 years (81,82). Though metformin-based intensive glycemic management reduces the risk of long-term complications when it is initiated for adults who already have diabetes (14), long-term follow-up studies of diabetes prevention trials have not demonstrated a significant reduction in microvascular or macrovascular complications associated with the use of metformin for type 2 diabetes prevention (53,55). Possible reasons for this discrepancy are discussed above.

The Indian Diabetes Prevention Programme clinical trial demonstrated a 26.4% relative risk reduction among participants with IGT who were randomized to receive metformin at a lower dose of 250 mg twice daily (83). A systematic review examined the effectiveness of metformin for diabetes prevention from seven clinical trials and post-hoc subgroup analyses (84). This study found that metformin reduced the risk of incident diabetes by 7%–32%, with higher risk reductions observed in the same subgroups that were identified in the DPP (84).

### Studies of Glucose-Lowering Medications Other Than Metformin

Multiple trials have evaluated the outcome of incident type 2 diabetes with other glucose-lowering medications also used in the treatment of type 2 diabetes, including alpha-glucosidase inhibitors (e.g., acarbose) (85), thiazolidinediones (e.g., troglitazone, rosiglitazone, and pioglitazone) (86,87,88), sulfonylureas and meglitinides (e.g., glipizide, glimepiride, nateglinide) (89,90), dipeptidyl-peptidase-4 inhibitors (e.g., sitagliptin and vildagliptin) (91,92), and glucagon-like peptide-1 (GLP-1) receptor agonists (e.g., liraglutide and semaglutide) (93,94) or dual-acting GLP-1 and glucose-dependent insulinotropic polypeptide (GIP) agonists (e.g., tirzepatide) (95). These medications have different mechanisms with ranging effects on insulin sensitivity and/or secretion. The sulfonylureas, meglitinides, and dipeptidyl-peptidase-4 inhibitors act primarily by increasing insulin secretion by pancreatic β-cells, without any clear effects on insulin sensitivity or favorable effects on body weight. In addition, the risk of hypoglycemia introduced by non-glucose-dependent stimulation of insulin secretion by sulfonylureas and meglitinides limit their relative value in type 2 diabetes prevention. Thiazolidinediones have direct effects on insulin sensitivity but may cause modest weight gain, fractures in postmenopausal women, and can increase the risk of heart failure, thereby diminishing enthusiasm for their use among large populations of people with prediabetes (81). The alpha-glucosidase inhibitors may result in modest weight loss but also have common gastrointestinal side effects, which limit their use, even among adults with type 2 diabetes. Finally, the GLP-1 and/or dual-acting GLP-1 and GIP agonists have promising potential for diabetes prevention mediated by glucose-dependent increases in insulin secretion and significant weight loss effects. Although GLP-1 medications do not seem to have significant direct effects on increasing insulin sensitivity, their weight loss effects (discussed separately below) have the potential to translate to lasting improvements in both insulin secretion and sensitivity, so long as weight loss is maintained. Although promising, there has been limited research to date involving sodium-glucose cotransporter-2 (SGLT2) inhibitors for diabetes prevention (96).

Additional studies have examined the effects of combining more than one medication class on diabetes risk reduction, usually consisting of metformin combined with another antidiabetic medication (87,97,98). One drug combination not yet studied includes a thiazolidinedione with an SGLT2 inhibitor, which is intriguing because of the potential for thiazolidinediones, such as pioglitazone, to directly improve insulin sensitivity, while the concomitant use of an SGLT2 inhibitor might mitigate the risks for modest weight gain and heart failure that have limited the use of thiazolidinediones for the past two decades.

GLP-1 receptor agonists (e.g., liraglutide, semaglutide) and dual GLP-1 and GIP agonists (e.g., tirzepatide) were developed as type 2 diabetes medications and are also associated with significant weight loss. In the SCALE trial, with approximately 61% of participants having prediabetes at baseline, liraglutide produced a mean weight loss that was 5.6 kg greater than with placebo (93). While this trial did not report rates of progression to diabetes or reversion to normoglycemia, it found beneficial changes in mean A1C (-0.23%) and fasting glucose (-6.9 mg/dL) for liraglutide versus placebo (93,99).

Early research on semaglutide and tirzepatide shows strong promise for diabetes prevention. Trials of these medications in adults with overweight or obesity but without type 2 diabetes have reported greater overall weight loss than earlier treatments. For example, more than 85% of trial participants who received semaglutide or tirzepatide lost at least 5% of their initial body weight, which is a threshold associated with meaningful glycemic improvements (100,101). In 2024, the STEP-10 trial of semaglutide among adults with obesity and prediabetes (defined by FPG 100–125 mg/dL or A1C 6.0%–6.4%) reported a mean 11.2% reduction in body weight at one year relative to placebo (102). In this trial, 81% of participants randomized to semaglutide reverted to normoglycemia at 52 weeks versus 14% in the placebo group (102). A 3-year trial of tirzepatide among adults with overweight or obesity and prediabetes (i.e., IFG, IGT, or A1C in the ADA-defined prediabetes range) demonstrated a mean 22.9% reduction in body weight with tirzepatide and a 94% reversion rate to normoglycemia (103). By demonstrating large amounts of weight loss and high short-term rates of reversion to normoglycemia, these trials highlight a potentially significant role for semaglutide and tirzepatide in preventing type 2 diabetes.

Published findings of randomized trials studying the effects of medications on the outcome of incident type 2 diabetes are summarized in Table 2. On balance, studies of the effects of antihyperglycemic medications other than metformin on type 2 diabetes prevention have reported clinically meaningful reductions in type 2 diabetes development, but only medications that also have meaningful weight loss effects, such as metformin and GLP-1 or GLP/GIP agonists, have proved to continue lowering incident diabetes risk after medications are stopped.

### Studies of Weight Loss Medications for Type 2 Diabetes Prevention

A smaller body of research has examined the role of a broader array of weight loss medications for preventing type 2 diabetes (Table 2), including lipase inhibitors (e.g., orlistat), phentermine-topiramate, and naltrexone-bupropion. Trials of orlistat demonstrated modest weight loss relative to placebo, as well as reduced diabetes incidence and higher rates of reversion to normoglycemia (104,105). Greater weight loss was observed in trials of combined phentermine-topiramate compared with placebo, with one trial demonstrating a 78.7% relative reduction in diabetes incidence (106,107). Naltrexone-bupropion produced similar weight loss without reporting glycemic effects (108). The data supporting GLP-1 receptor agonists and GLP-1/GIP dual agonists for type 2 diabetes prevention are discussed in the Studies of Glucose-Lowering Medications Other Than Metformin section.

Many more weight loss medications are currently in development, including new GLP-1 receptor agonists, other incretin mimetics, cannibanoid receptor modulators, and those with different mechanisms. Future research will be needed to evaluate their role for type 2 diabetes prevention, potentially expanding the landscape of available medication options for prediabetes treatment.

### Disentangling Glucose-Lowering Effects Alone From Primary Prevention

There has always been some controversy regarding the role of antidiabetes class medications for diabetes prevention. When these drugs are actively being taken, most lower blood glucose by directly increasing insulin secretion or improving insulin sensitivity reversibly while the drug remains bioavailable. If these medications are observed to have more lasting effects, through mechanisms such as weight loss or by preserving β-cell mass and responsiveness, then they likely have stalled or delayed the pathophysiological process leading towards type 2 diabetes. However, if effects are not durable after the drug is withheld for a short time, then this approach is akin to initiating diabetes treatment earlier, rather than actually preventing it. Some efficacy trials of pharmacotherapies for diabetes prevention have attempted to answer this question by conducting “wash-out” studies that withdraw the medication until it is no longer bioavailable and then reassess diabetes status. One prominent example is provided by the DPP. Upon completion of trial’s final assessment, DPP participants randomized to the metformin arm who had not yet developed type 2 diabetes were asked to stop their medication for 1–2 weeks and return for a reassessment; 48 out of 668 participants tested positive for diabetes following this brief wash-out interval. Taking these new cases of incident diabetes into account, the risk reduction estimate for metformin treatment was lowered from 31% to 25% (109). Some argued that this 1–2-week period was too brief to definitively examine whether metformin’s diabetes prevention effect was durable after stopping the medication, while others argued that the residual risk reduction may have been driven by the modest weight loss experienced by metformin participants.

Other trials involving treatment with antidiabetic medications conducted longer wash-out studies ranging from 10 to 52 weeks (85,110,111,112), generally discovering that the medications’ effects on lowering type 2 diabetes incidence were no longer evident. One meta-analysis pooled data across six of these large wash-out studies, including DPP, and reported that the prevention effect was no longer significant after discontinuing the medications (relative risk 0.95, 95% CI 0.79–1.14) (113). By contrast, trials of semaglutide demonstrated reductions in insulin resistance, which were mediated primarily by weight loss (114). The STEP-10 trial found that 81% of participants taking semaglutide reverted to normoglycemia after 52 weeks of treatment, but this proportion decreased to 44% after participants discontinued the medication for 28 weeks (102). These data suggest that a potential type 2 diabetes prevention effect may remain after discontinuing semaglutide, depending on the duration of weight loss maintenance. The bariatric surgery literature also reports long-term remission of type 2 diabetes with sustained weight loss that is comparable to findings after treatment with semaglutide and tirzepatide (115,116). Because prior research has demonstrated that weight loss can improve insulin sensitivity and may be protective of ß-cell function, it is possible that these medications will have a more durable impact on altering the underlying pathophysiology of prediabetes and type 2 diabetes development.

### Clinical Research on the Efficacy of Bariatric Surgery for Type 2 Diabetes Prevention

A large body of research has demonstrated the effectiveness of metabolic and bariatric surgeries on weight loss and diabetes remission. The most effective surgical procedures produce weight loss of 25%–35% from preoperative weight (117), which is much larger than the weight loss observed after intensive lifestyle interventions and most pharmacotherapies studied for type 2 diabetes prevention. The magnitude of weight loss and the associated rates of diabetes remission vary according to the type of bariatric surgery performed, with the best outcomes observed after Roux-en-Y gastric bypass, biliopancreatic diversion, and to a lesser degree, laparoscopic sleeve gastrectomy (36,37). Prior research has elucidated central and peripheral mechanisms by which bariatric surgeries exert their glycemic effects, including rapid changes in glucose utilization, the intestinal microbiome, and gut hormones, including incretins (38). These physiologic changes result in significant weight loss, thereby improving insulin sensitivity and enhancing ß-cell function (38).

Many studies among adults with type 2 diabetes have reported rates of remission after bariatric surgery ranging from 30% to 78% at 1 year (115,116,118). This literature is complicated by different definitions of type 2 diabetes remission, as reflected in changing consensus guidelines over the last 2 decades (119,120). One large Swedish study of bariatric surgery examined 10-year rates of incident type 2 diabetes among adults with a mean preoperative BMI of 42.4 kg/m^2^ and no prior evidence of type 2 diabetes. This study did not report the baseline prevalence of prediabetes. Compared with matched controls, those who underwent bariatric surgery experienced an 83% relative risk reduction in type 2 diabetes development, with some of the largest effects among participants with IFG at baseline (121). While there have not been large randomized controlled trials of bariatric surgery for type 2 diabetes prevention, this effect has scientific plausibility and has been observed in smaller case studies (122,123). Bariatric and metabolic surgeries, therefore, represent one potential option for diabetes prevention, especially among individuals with obesity who have not responded well to lifestyle intervention and pharmacotherapy. Health economic studies suggest that bariatric surgery represents a cost-saving treatment for obesity and diabetes over the long term (124,125). However, to our knowledge, the cost-effectiveness of bariatric surgery has not been evaluated specifically for type 2 diabetes prevention among individuals at high risk.

Important characteristics differentiating major behavioral, pharmacological, and surgical interventions with evidence for effectiveness in the primary prevention of type 2 diabetes among high-risk adults are summarized in Table 3.

## Research to Translate Clinical Trial Interventions Into Real-World Practice and Population Health

Efficacy trials, such as the DPP, raised tremendous enthusiasm that intensive lifestyle interventions, if offered on a population scale, could reduce the U.S. incidence of type 2 diabetes by as much as 1 million people annually. Naturally, this enthusiasm directed immediate attention towards the need for carefully designed implementation strategies that would enable DPP-like interventions to be more feasible, acceptable, and financially sustainable in real-world settings. This included pragmatic changes to the eligibility criteria, delivery methods, and resulting outcomes, as discussed in-depth in this section. The desire to deliver DPP in real-world settings catalyzed a new era of “DPP translation” research aiming to design, demonstrate, and improve implementation strategies over time (126). The following sections consider the context, the stakeholders, and how their goals and interests shaped implementation efforts, beginning in about 2002, when the DPP was published.

### Finding “Fit” Between DPP Implementation Demands and Real-World Delivery Organizations

Almost 25 years ago, the earliest efforts to translate research regarding the benefits of intensive lifestyle interventions identified two major challenges. First, randomized controlled trials had used the OGTT to identify eligible participants, which pointed to an important role for the healthcare sector to identify high-risk adults. However, the healthcare sector lacked the facilities, personnel, or payment systems to administer longitudinal behavioral intervention services involving weekly to monthly return visits with professionals with expertise in not only diet and physical activity prescriptions but also behavioral coaching that addressed the knowledge, skill-building, emotional support, and problem-solving needs of individuals attempting to change and maintain healthier lifestyle behaviors. Second, the DPP lifestyle intervention faced several implementation constraints: (1.) It was unlike other services already being offered in health systems; (2.) there was not a workforce of health coaches routinely available in health systems; (3.) profound competing demands limited the additional time health professionals could spend on primary prevention activities (127); and (4.) health insurance did not routinely reimburse health systems for educational and behavioral services. These challenges catalyzed the exploration of alternative delivery channels for DPP-like interventions, recognizing that the health system would still need to perform critical adjunctive roles, such as performing blood tests to identify the target population and encouraging those at high risk to engage in DPP-like services that may be offered elsewhere (e.g., case finding and referral) (128).

The YMCA of the USA was identified as a potential partner to plan and support a national network of DPP delivery organizations because it: (1.) had a mission to promote health and wellness; (2.) supported a workforce with expertise in lifestyle behavioral coaching; and (3.) was already organized as a vast network at both regional and national levels, thereby enabling the possibility of large-scale program delivery (129). However, the YMCA had little experience partnering with the healthcare sector to offer services to “patients” who might be referred by a doctor because of an abnormal glycemic test. Although the YMCA had confidence in its ability to deliver high-quality lifestyle intervention programming to large populations, it was concerned about the potential administrative burden and reimbursement structure, especially for participants who were not dues-paying members. The YMCA also expressed interest in modifying the intervention structure to improve the feasibility of offering DPP-like interventions in a typical YMCA facility.

### Adapting DPP-Like Interventions to Improve Implementation Feasibility and Sustainability

Early reports suggested that lifestyle intervention delivery approaches used by clinical efficacy trials would be very costly to replicate (130). Many individuals with prediabetes lived in lower income, minoritized community settings or were older adults. If these individuals were required to pay fees to access the services, those costs would impose an unfair disadvantage that prevented those at disproportionately high risk for type 2 diabetes to access and benefit from DPP-like interventions. For these reasons, it was important to consider how to reduce overall delivery costs, ideally without diminishing program efficacy.

To alleviate the financial burden on participants, it became important to explore opportunities for reimbursement by third parties, such as public and private health insurance plans, as well as employers that already were making large investments in workplace wellness and other health and wellness benefits for employees. Importantly, third parties had to consider how the cost of paying for those services would be funded. All health insurance plans and programs operate largely on annual budgets funded by revenues collected from employers, employee payroll deductions, or public tax revenues. In order to add a new coverage benefit for DPP-like services, the third party would either need to reduce expenditures for other services or increase what it charges employers, employees, or taxpayers. Though most adults with overweight or obesity and prediabetes can benefit directly from receiving services that support healthy lifestyle changes and weight loss, this population is very large (nearly 30 million U.S. adults meet eligibility criteria for the DPP and 100 million overall have prediabetes) (131), so the total budget implications would be significant, unless the target population were narrower. These considerations led third party payors to be cautious about the specific characteristics of individuals who would receive the benefit and how they might structure service provider reimbursement to ensure high service quality and maximize desired outcomes (132).

All of these considerations had powerful effects on shaping implementation strategies in the United States over the past 20 years, including the establishment of a Diabetes Prevention Recognition Program, as part of the CDC’s National Diabetes Prevention Program (NDPP), to identify and support high-fidelity and high-performing suppliers of DPP-like intervention services nationally. Cost considerations and public budget impacts also informed specific policy requirements set by payors such as Medicare, which imposes additional restrictions on suppliers, eligible participants, and the duration of DPP services offered to beneficiaries (133). In the next section, we provide an overview of past and current research to inform implementation strategies for evidence-based intensive lifestyle interventions for diabetes prevention in the United States.

### The Dawn of Translational Research in Type 2 Diabetes Prevention

Translational research beginning in about 2003 focused on carefully designing and evaluating adaptations to the DPP’s eligibility criteria and intervention protocols to improve implementation and scaling of this evidence in real-world delivery settings and to reach at-risk populations throughout the United States. Strategies included broadening eligibility criteria, adapting interventions from individual- to group-based delivery, training community organization employees or paraprofessionals to serve as coaches, rather than highly trained research professionals, reducing the frequency and duration of coaching contact-hours after the first 6–12 months, and using weight change as a primary intermediate outcome defining effectiveness (134,135,136,137,138,139,140,141,142,143,144). Development of the Prediabetes Risk Test by the CDC and ADA facilitated identification of eligible individuals (145), following an approach similar to that used in some European countries (146,147). Many programs overcame the OGTT eligibility barrier by adopting more pragmatic eligibility criteria, such as IFG or elevated A1C alone, while others enrolled many participants based only on a risk score.

With significant investment by the U.S. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK) and other funders, translational research programs across the United States examined the implementation of DPP-like intensive lifestyle interventions in doctors’ offices and hospitals, as well as YMCAs, churches, workplaces, senior centers, and other community-based organizations. Some studies focused on hard-to-reach and vulnerable populations, including those living in low income urban or rural communities, older adults, and women with a history of gestational diabetes, to name a few. Additional studies examined different delivery methods, such as virtual group sessions, on-demand programs accessed through smartphone apps and even cable television, and digital programs that include gamification (148). (See more detail on digital DPP programs in the Current Scope and Performance of NDPP-Recognized Organizations and MDPP Suppliers section.)

Translational studies generally demonstrate less weight loss than landmark clinical trials like the DPP (149,150,151), which likely relates to the lower frequency and duration of contact hours, as well as enrollment of participants with lower motivation and greater social barriers than clinical trial volunteers. Mean weight loss estimates from systematic reviews of intensive lifestyle interventions offered in community-based settings have averaged around 3% from baseline (149,150,151,152,153). Post-hoc analysis of the DPP identified a graded relationship between weight loss and diabetes risk; for the DPP population, every 1 kg (i.e., about 1%) of weight loss was associated with a 16% further decrease in relative risk of incident type 2 diabetes (56), demonstrating that the level of weight loss achieved in most translation trials remains clinically meaningful. Importantly, although lower-intensity, real-world adaptations of the DPP achieve only about half the mean weight loss as in efficacy trials, the delivery costs of these programs are roughly 25%–50% of delivery costs during the DPP (42,154). Thus, real-world implementation of DPP-like interventions reaches larger and more diverse participants than clinical trials and achieves more modest, but clinically meaningful, levels of weight loss but offers equal or greater “value” to those who fund it, reflected by a lower average delivery cost to achieve 1 kg of weight loss.

Importantly, while the DPP and other landmark trials identified weight loss as the dominant predictor of type 2 diabetes prevention, no translational studies have reassessed this association in the generally lower-risk populations targeted by translational research, many of whom may not have IFG or the combination of more specific metabolic defects (muscle insulin resistance and insufficient β-cell insulin secretion following a meal) that underlie IGT (47). Acknowledging this limitation, the findings of early translational studies still served to frame the feasibility, effectiveness, and reach of real-world implementation of DPP-like intervention programs and catalyzed even greater interest in achieving national scale.

### Taking Things to Scale—Advancing U.S. Policies Towards Population Diabetes Prevention

The decade from 2003 to 2013 witnessed several related efforts aimed at delivering evidence-based intensive lifestyle programs on a national scale. From late 2003 to 2007, investigators at Indiana University collaborated with the YMCA of USA and YMCA of Greater Indianapolis to adapt the DPP curriculum to improve the feasibility and appropriateness of delivery by YMCA wellness instructors. The adapted intervention preserved the session goals and content for all 16 of the DPP’s core curriculum visits. The format, however, was converted from one-on-one coaching to delivery to groups of 8–12 participants (155). The team also collaborated on a competency-based training curriculum suitable for preparing YMCA wellness instructors to deliver the DPP intervention (137). Finally, because of cost constraints and concerns regarding appropriateness, the team removed the use of toolbox incentives, which in the DPP had included supplying home exercise equipment, nutritionist advice regarding more structured eating plans, and liquid formula meal replacements (57). With critical support from several NIDDK-funded grant awards, this collaboration demonstrated the feasibility, fidelity, and preliminary effectiveness of the “YMCA’s DPP” (134).

In mid-2009, the DPP translational research team at Indiana University with personnel from NIDDK and the CDC Division of Diabetes Translation convened a national stakeholder meeting to share emerging results from both efficacy trials and early translational research, as well as to seek stakeholder recommendations needed to advance the scaling of DPP-like programs nationally. The meeting in Indianapolis included leaders from YMCA of the USA, UnitedHealth Group, other insurers and large employers, and federal agencies, including the Agency for Healthcare Research and Quality, which supports the U.S. Preventive Services Task Force (USPSTF). Following this meeting, leaders from UnitedHealth, the YMCA, and the CDC collaboratively designed a nationwide demonstration project to deliver the YMCA’s group-based adaptation of the DPP to commercial health plan enrollees in 23 states (156). Participants were identified using glycemic results from healthcare and worksite screening, and the YMCA delivered all of the intensive lifestyle intervention components, with reimbursement from UnitedHealth using a performance-based payment approach.

While this demonstration project was being launched, the ACA was signed into law in March 2010, authorizing funding for the CDC to establish the NDPP. This represented the first federal investment in national infrastructure to improve the adoption and implementation of DPP-like interventions for type 2 diabetes prevention. From 2010 to 2011, the CDC assembled DPP investigators, service delivery organizations, payors, and other stakeholders to develop minimum fidelity requirements for eligible participant characteristics, curriculum components, delivery format, and contact intensity. The NDPP also developed infrastructure to support: (1.) workforce development to train lifestyle coaches to deliver the group-based program; (2.) a recognition program for publicly identifying organizations that deliver the program with fidelity and achieve clinically significant outcomes; (3.) tools and technical assistance to support capacity building, data collection, and reporting requirements needed for NDPP delivery and recognition; and (4.) marketing through multiple channels to support program uptake (157). The NDPP published standards for delivery organizations that guided training of lifestyle coaches, participant eligibility, curricular materials, program structure, and measured outcomes required to achieve recognition as a NDPP provider (158). Organizations can receive three levels of program recognition—preliminary, full, or full-plus—which refer to the progress made with respect to meeting these standards, including defined cutoffs for participant retention, weight change, and A1C change. Those with full or full-plus recognition can request insurance reimbursement for delivering the program (159).

The ACA included two additional components that proved highly relevant to DPP scaling efforts in the United States. First, it established a U.S. Centers for Medicare and Medicaid Services (CMS) Innovation Center, tasked to administer awards to support large-scale tests of innovations in health service delivery and organization. The ACA also gave CMS authority to make Medicare funding decisions for services shown by an Innovation Center demonstration project to be effective and either cost-neutral or cost-saving for the Medicare program. In 2012, the CMS Innovation Center funded the YMCA of USA and its partners to enroll Part B Medicare beneficiaries with prediabetes into the YMCA’s DPP in eight states. This 3-year demonstration proved effective and was deemed cost-neutral or cost-saving by the CMS actuarial office (160,161). Earlier cost-effectiveness analyses from the DPP and subsequent translational trials also had reported favorable costs per quality-adjusted life year (162). These findings paved the way for subsequent CMS policies to support a Medicare Diabetes Prevention Program (MDPP) and enabled Medicare to reimburse recognized MDPP suppliers, which could include non-healthcare organizations (163). Second, the ACA mandated that all USPSTF Recommendations with an “A” or “B” evidence rating must be covered by Medicare, state Medicaid programs, and most commercial, employer-sponsored health plans nationally, at no out-of-pocket cost. This rule became important when, in 2014, the USPSTF issued a grade “B” recommendation that individuals at high risk for cardiovascular disease, including adults with prediabetes, be offered intensive lifestyle counseling services (163). The DPP lifestyle intervention was highlighted in this 2014 recommendation as one of two evidence-based intensive lifestyle interventions. According to the recommendation, healthcare providers could refer patients to lifestyle interventions offered outside the healthcare sector.

Today, the NDPP maintains a network of almost 1,400 organizations nationwide, including 112 different regional YMCA associations (164). A diverse array of other recognized NDPP providers include smaller community-based organizations, churches, public health departments, tribal health organizations, academic health systems, federally qualified health centers, large health networks (e.g., Kaiser Permanente), and digital providers. Over the past 15 years, many large employers and the commercial insurers have made DPP-like interventions available as a health benefit, especially those offered through digital platforms (165), using multiple strategies to fund or reimburse program delivery. Medicare began reimbursement of MDPP suppliers in 2018 (133,166). Moreover, 29 states and the District of Columbia currently support DPP reimbursement for Medicaid enrollees with prediabetes (167,168,169). Most of these third-party payors require delivery organizations to be part of the NDPP’s Diabetes Provider Recognition Program (158), which serves to validate that the programs they offer meet the minimum standards for content, intensity, and duration, while monitoring and reporting the eligibility criteria and outcomes for visit completion and mean weight loss (133). These critical components contribute to an ever-evolving national infrastructure for type 2 diabetes prevention that provides important opportunities for practice improvement and policy-relevant future research.

In spite of these remarkable advances in U.S. capacity to bring evidence-based intensive lifestyle programs to high-risk adults, significant administrative challenges remain for DPP delivery organizations to recruit and retain participants, report data to multiple stakeholders, and receive sufficient reimbursement from payors. These challenges likely limit the pool of potential provider organizations and threaten their financial sustainability. Many of these challenges are discussed further in the next section.

## Existing Activities and Implementation Challenges in U.S. Diabetes Prevention

### Current Scope and Performance of NDPP-Recognized Organizations and MDPP Suppliers

As of June 2025, the NDPP recognized 1,389 individual community and healthcare organizations as offering 1,555 different high-fidelity, DPP-like interventions across the United States (170). From 2012 to 2016, NDPP data demonstrated an average weight loss of 4% among participants, based on information from 35,844 adults enrolled across 435 CDC-recognized organizations that delivered the program in person (171). Participants achieved an average of 152 minutes of self-reported physical activity per week, with 41.8% meeting the weekly physical activity goal of 150 minutes (171).

In 2015, the NDPP expanded its implementation strategies for the program beyond in-person group sessions to increase accessibility and flexibility for participants (172). These expanded strategies now encompass distance learning via live, synchronous video conferencing; asynchronous or non-live, online engagement where participants access program content at their convenience through phones, tablets, or laptops; and hybrid delivery approaches that involve multiple approaches (referred to as “combination”). Both synchronous and asynchronous delivery modes have been supported by translational research, stakeholder input, and gray literature as feasible and effective strategies for achieving clinically meaningful weight loss and glycemic improvements (173,174,175). While these remote options have been increasingly adopted, in-person participation remains a predominant method of NDPP delivery. Among the 1,555 programs registered on the NDPP website in June 2025, 741 (48%) were delivered entirely through live, in-person group sessions with a lifestyle coach. Smaller proportions of programs used alternative delivery methods: 187 (12%) were delivered entirely through live, distance learning; 482 (31%) were delivered through a combination of in-person and live distance learning; 91 (6%) were delivered entirely through, non-live, online channels; and 54 (3%) were delivered through other combined channels that were at least partly online and non-live (170).

Data collected from 333,715 participants between 2012 and 2018 show some variation in weight loss across the NDPP’s different delivery modalities (176,177): participants in the in-person modality achieved an average weight loss of 4.4%, while those in the distance-learning format averaged 4.7%. Online participants, however, averaged 2.6% weight loss, and those in the combination modality (a combination of any of the three modes) reported a 2.9% average weight loss. Among participants meeting the 5% weight loss goal, 38.2% were in the in-person group, 40.6% in distance learning, 22.2% online, and 23.2% in the combination modality. Physical activity levels also differed by delivery mode: distance-learning participants reported the highest average weekly activity at 197.4 minutes, followed by in-person participants (169.3 minutes), online participants (163.2 minutes), and combination participants (147.2 minutes). Overall, participants who attended more sessions achieved greater average percent weight loss and higher weekly physical activity minutes.

NDPP services are now available in nearly all U.S. states and territories (170). However, prior research has identified geographic disparities in the availability of the NDPP, which may lead to differential access to the program. For example, U.S. counties marked by high diabetes incidence and low socioeconomic status appear to have lower availability of NDPP services (178). Access to the NDPP program is also limited in rural areas, with fewer than 15% of rural counties offering the program compared to almost half of urban counties (179). A 2025 study reported that NDPP delivery organizations located in counties with higher social vulnerability were less likely to have programs fully recognized by the CDC (159), highlighting prevailing challenges for many U.S. communities to have fair access to diabetes prevention services. A large body of public health research has demonstrated disparities in diabetes risk among U.S. adults from racial and ethnic minority groups, who are more likely to be affected by unemployment, poverty, unstable housing conditions, limited community service access, transportation barriers, and lower access to broadband communication networks. Thus, the finding of fewer high-fidelity NDPP services in communities with high social vulnerability has implications for widening preexisting disparities in diabetes incidence, and this represents an important area of ongoing focus for both research and delivery system improvement.

Supply side challenges are also observed in the MDPP, which requires suppliers to meet additional recognition and reporting requirements put forth by CMS. CMS only provides payment when MDPP suppliers have NDPP recognition, deliver the intervention in-person or using a synchronous distance-learning approach, and both the organization and coach have received a CMS National Provider Identifier (180). As of July 2025, there were 288 MDPP suppliers across the United States (only 21% of the 1,389 recognized NDPP organizations), offering services at 909 locations (181). Supporting a sufficient number of capable MDPP suppliers has remained a challenge for CMS, as the current capacity is insufficient to serve the 30 million Medicare beneficiaries with prediabetes (182). Notably, 39% of all Medicare beneficiaries reside more than 25 miles from the nearest MDPP location, presenting significant geographic access challenges for older adults (161). These challenges were highlighted by a 2022 report delivered to Congress by the National Clinical Care Commission (NCCC), including recommendations that MDPP supplier requirements be harmonized with the less restrictive NDPP recognition requirements, to provide Medicare beneficiaries with prediabetes broader access to high-fidelity lifestyle interventions for diabetes prevention (183).

A 2022 report evaluated MDPP data through 2021 with respect to participation, weight loss outcomes, and its impact on Medicare expenditures and diabetes incidence (161). MDPP participants achieved an average weight loss of 5.1%, with 53% of beneficiaries meeting the program’s goal of at least 5% weight loss. The same analyses did not demonstrate a change in Medicare expenditures before and after MDPP participation when compared to a matched group of nonparticipants, which may have been related to low statistical power to evaluate cost outcomes. The report suggests that cost savings may be demonstrated as more beneficiaries enroll in the program and as the time since their initial participation increases. Currently, MDPP has not yet had sufficient participation or duration to determine whether it significantly reduces diabetes incidence or improves healthcare expenditures among beneficiaries.

### Current Volumes and Representativeness of NDPP Participants

Despite the national growth in NDPP-recognized delivery organizations overall, the proportion of eligible Americans who take part in those programs remains quite limited. As mentioned above, initial scale-up of the DPP starting in 2010 was accomplished through a partnership involving UnitedHealth Group and the YMCA, in collaboration with the CDC (129,156,184). This partnership leveraged YMCAs as a national network for DPP delivery, a mechanism for sustainable reimbursement through a major health insurance administrator, and capacity-building and administrative support from a national public health agency. In less than 2 years, the YMCA DPP was scaled to 46 communities across 23 states, and more than 500 YMCA Lifestyle Coaches were trained (156). During that time, 2,369 participants were enrolled, with 1,723 (72.7%) completing the entire core program, which has been a common metric for those reaching a “dose” of NDPP exposure associated with improved weight loss success (149). Among those completing the program during this first national rollout, average weight loss was approximately 5% (156).

The ensuing years witnessed even greater participation under the NDPP. As of 2019, the YMCA alone reported that more than 68,000 high-risk adults had attended at least one DPP session (184). According to publicly available participation data for all NDPP delivery organizations, nearly 819,000 people enrolled in NDPP intensive lifestyle interventions between January 2012 and April 2025 (170,172,177). Although these data highlight substantial growth in DPP participation, it is important to note that NDPP recognition only requires that 35% of participants have documentation of a blood test confirming prediabetes, with the remainder of participants qualifying based on self-reported risk factors alone. Thus, it is assumed that far less than 1% of the 97.6 million American adults living with prediabetes today have taken part in a DPP-like intervention. Although NDPP interventions appear to have meaningful health promotion benefits for the high-risk individuals who participate, the relatively low overall reach limits its potential effectiveness to lower type 2 diabetes incidence at a population level (185).

NDPP programs face challenges not only with enrollment but also with retention. Higher session attendance has been consistently associated with improved outcomes (149,186). Program attrition generally tends to be gradual throughout the program, with peaks after the first session and again after completion of the 16-week core curriculum, when session frequency decreases from weekly to monthly (187). Analyses of NDPP participants from 2012–2018 showed variable retention by delivery mode: median number of sessions attended was 16 (interquartile range [IQR] 8–21) for in-person, 10 (IQR 4–17) for online, 11 (IQR 6–19) for distance learning, and 9 (IQR 3–17) for combined delivery modes (176). Average weight loss gradually increased by number of sessions attended for all delivery modes (176), underscoring the importance of visit completion and retention regardless of delivery modality. Men had a higher prevalence of prediabetes than women (41% vs. 32%, respectively), yet they comprised only about one-fourth of NDPP participants (172). Younger adults were underrepresented in the NDPP; online and distance-learning programs show promise for increasing participation of adults age 18–44 years, but retaining them may be more difficult (177). Similarly, while the representation of Hispanic/Latino adults in the NDPP roughly approximates their proportion in the U.S. population (13% vs. 18%) (172), their retention rates in the program are the lowest among all racial and ethnic groups (177).

Disparities in program effectiveness also exist for different racial and ethnic populations. For example, non-Hispanic White adults using in-person NDPP programs experience an average body weight loss of 5%, whereas racial and ethnic minority groups report weight loss around 3% (177). Efforts to improve participation and effectiveness among social minority groups will likely need to address the barriers that limit their engagement, including social and economic disadvantages, cost, transportation challenges, language barriers, different cultural preferences, and less social support, all of which have been well documented in the literature (188,189) and previously reported by individuals with prediabetes (190,191,192).

### National Data on Metformin Use for Type 2 Diabetes Prevention

Notably, the generally low rates of implementation and uptake also extend to the use of metformin for diabetes prevention (193,194,195,196). Using nationally representative data from 2005–2012, the age-adjusted prevalence of metformin use was 0.7% among adults with prediabetes, which is similar in magnitude to rates of DPP participation in the prediabetes population (194). Though metformin use appears greater among adults with higher BMI and more severe dysglycemia, metformin use was still low among those with BMI ≥35 kg/m^2^, a group for whom metformin is more highly recommended (194). Use of metformin was similar by race, poverty-to-income ratio, and educational attainment (194). Prescription rates for metformin from insurance claims data are slightly higher, though still low. For example, in a national sample of 17,352 working-age adults with prediabetes who were continuously insured from 2010 to 2012, 3.7% were prescribed metformin (193). After adjusting for age, income, and educational attainment, women and adults with obesity were nearly twice as likely to be prescribed metformin, and those with two or more comorbid cardiometabolic conditions received metformin prescriptions at nearly the same rate (193). More recent data show similarly low patterns of use; in a 2012–2018 analysis of 53,551 patients with prediabetes from the IBM MarketScan research database, 2.4% of patients received a metformin prescription within 1 year of laboratory-confirmed prediabetes (195). In a study of more than 1 million U.S. veterans with incident prediabetes, 1.1% were prescribed metformin during an average of 3.4 years after diagnosis (196).

Low uptake of metformin in the United States may be explained by multiple factors, such as clinical practice recommendations that in many ways frame it as a second-line alternative to lifestyle interventions (6), low clinician and patient awareness, and preferences to prevent or delay additional medication use, rather than to adopt a medication for primary prevention. The USPSTF includes both intensive behavioral interventions and metformin as effective preventive strategies in its most recent (2021) grade “B” recommendation that clinicians should offer or refer overweight and obese adults with prediabetes who are between ages 35 and 70 years to effective preventive interventions (197), although they highlight the prevailing barrier that metformin has not received approval for type 2 diabetes prevention by the FDA. The fact that metformin use for type 2 diabetes prevention is considered “off-label” prescribing is likely to contribute to its limited use in the clinical community.

### Strategies to Improve Reach of Diabetes Prevention, Overall and Among High-Risk Groups Facing Access Barriers

Reach is defined as the proportion of eligible people who participate in an intervention and how representative they are of the target audience (198). We organize strategies to improve reach into three key areas: (1.) efforts to increase prediabetes screening and awareness; (2.) adjunctive strategies to motivate and prepare eligible adults to decide upon and engage in evidence-based lifestyle or medication interventions; and (3.) diversification of NDPP delivery modalities and content to appeal to more diverse individuals and groups with different preferences and abilities.

#### Efforts to Increase Prediabetes Screening and Awareness

A critical prerequisite for participation in a DPP-like intervention program is to be identified with prediabetes or another high-risk classification, based on a recent blood test or positive risk screening questionnaire, and to be aware of one’s risk and treatment options. Efforts to increase screening for and identification of prediabetes represent a critical component of national type 2 diabetes prevention efforts. The ADA updates annual clinical practice recommendations for prediabetes and diabetes screening (12), and the USPSTF has since 2014 issued a “B” evidence-rating and recommended targeted prediabetes and type 2 diabetes screening by healthcare providers, which has implications for reimbursement by health insurance plans and programs. The USPSTF now recommends screening all adults age 35–70 years who have overweight or obesity (197). The recommendation also indicates that clinicians should consider earlier screening for adults at highest risk of developing type 2 diabetes (i.e., at younger ages or lower BMIs), including racial and ethnic minorities, women with a history of gestational diabetes, or other type 2 diabetes risk factors. The ADA clinical practice recommendation advises broader screening for adults age ≥35 years (i.e., regardless of BMI) and those who are age <35 years and have additional type 2 diabetes risk factors.

Analysis of national survey data from 2013–2018 estimated that approximately 90 million U.S. adults met the eligibility criteria for glucose testing as outlined by the USPSTF; almost twice as many (approximately 170 million) were eligible according to the ADA guidelines (199). On average, approximately one-half of eligible adults report having undergone glucose testing within the past 3 years, and the proportion screened has changed very little over time (200). However, the likelihood of screening has been lower for younger adults, men, those who identify as Hispanic/Latino, those with less than a high school education, individuals living in poverty, and those without health insurance or a usual place of care (199). Studies using electronic health care records illustrate highly variable estimates of screening completion among eligible patients, ranging from 14% to 78% across differing health system settings and populations (201,202,203,204). Improving screening performance overall and reducing variation across health systems and populations are priorities for national efforts to identify and prevent type 2 diabetes.

Completion of a laboratory screening test and being informed and aware of prediabetes are not the same. While screening identifies those at risk, awareness is essential for initiating healthy lifestyle changes and connecting individuals to preventive care services (128,199). Despite the importance of prediabetes awareness for the success of type 2 diabetes prevention efforts, a large majority of people with prediabetes remain unaware of having the condition. Reasons for low rates of prediabetes awareness are multiple, including not being screened, breakdowns in a clinician recognizing prediabetes, even when a test is “positive,” and missed opportunities or ineffective strategies for communicating test results to patients in ways that are understandable (128). Some data suggest that communication and brief counseling are performed with only about one-third of adults with prediabetes (205,206). Although awareness remains low, it has increased very slowly in recent years (Figure 2). In 2005–2008, only about 7% of adults with prediabetes were aware of their condition (207), rising to 11% in 2011–2014 and 17% in 2017–2020, according to the most recent nationally representative data (3). These gains may reflect gradual adoption of ADA and USPSTF recommendations, along with professional education and advocacy efforts by the American Medical Association (AMA) in partnership with advertisers and marketing groups (208). For example, the AMA has developed prediabetes quality measures for clinicians that assess efforts to offer an evidence-based lifestyle intervention, including the NDPP, for patients with prediabetes (209). Systems-level interventions that follow a population health approach for patients with prediabetes may represent an effective strategy for identifying those eligible for the NDPP, while also promoting their awareness of the condition and its treatment.

While awareness remains very low across most high-risk patient groups, disparities also persist. For example, adults with lower educational attainment, particularly those who did not complete high school, report lower levels of awareness compared to their more educated counterparts. In 2005–2010, only 6% of adults with prediabetes who did not have a high school diploma were aware of having prediabetes compared to 10% of those with educational attainment greater than high school (210). More recent data from 2011–2020 showed improvement overall but a persisting gap: 11.5% of those without a high school education were aware versus 15.4% of those with higher educational attainment (211). As mentioned, the CDC and ADA have an online Prediabetes Risk Test (145) intended to increase awareness of type 2 diabetes risk. While prior research suggests reasonable performance of this tool to identify those with prediabetes (212), data on whether its use has improved prediabetes awareness nationally are lacking. Additional efforts are needed to improve prediabetes awareness overall and to close prevailing disparities by socioeconomic and other patient characteristics.

#### Adjunctive Strategies to Motivate and Prepare Eligible Adults to Engage in Evidence-Based Diabetes Prevention Services

Adjunctive implementation strategies refer to approaches that likely have no direct effect on a desired outcome, in this case type 2 diabetes prevention, but serve to enhance attitudes and behaviors to engage with another intervention that can achieve that outcome (213). One relatively simple adjunctive strategy adopted by the CDC to encourage and support NDPP participation was the creation of an interactive, personalized, web-based Personal Success Tool aimed at improving retention (214). Another common innovation has been for programs to introduce a “Session Zero” or “Discovery Session” that is delivered before enrollment and aims to enhance participants’ interest in the program, thereby improving the effectiveness of recruiting, enrolling, and engaging participants longitudinally (151,215,216). One study found that new NDPP enrollees who attended a Discovery Session, compared with new enrollees who did not attend such a session, stayed engaged as a participant for 99.8 more days and experienced 2.0% greater weight loss (217). In a 2020 survey, 79.5% of NDPP delivery organizations reported using a Discovery Session, with 81.1% using it as a recruitment strategy and 72.8% using it as an orientation session (218).

Health systems have employed a number of strategies to increase motivation and encourage program enrollment and retention, including office-based brief educational sessions, telephonic outreach education, and offering the equivalent of a Discovery Session to motivate and prepare eligible patients even prior to linking them with a program (219,220). Research has focused on the development and testing of shared decision-making strategies in primary care settings, where most prediabetes diagnoses occur. One example is the Prediabetes Informed Decision and Education (PRIDE) Trial, a cluster randomized controlled trial conducted across 20 primary care clinics within a large health system in California (221). In this trial, patients participated in a face-to-face, shared decision-making visit with a pharmacist, who used a decision aid to explain prediabetes and present options for treatment, including metformin and the DPP. Results from the study demonstrated that exposure to the decision-making visit resulted in a significant increase in both DPP participation and metformin uptake. Another study evaluated a printed prediabetes decision aid for improving patients’ knowledge of treatment options and intentions to engage in an intensive lifestyle program and/or metformin use (222). Preliminary findings indicate a significant reduction in decisional conflict and an increase in patients’ intention to participate in intensive lifestyle interventions (223).

#### Expanding Access and Delivery Channels Using Technology

The past 15 years have seen considerable expansion of technology-mediated diabetes prevention interventions (174,175,224). With increasing internet access and smartphone use (225,226), interventions delivered via on-demand videos, web pages, smartphone apps, and text messaging are becoming more prevalent. On-demand video programs enable users to access session content at greater convenience (144). Moreover, web-based and app-based programs offer additional interactive tools, such as goal tracking, reminders, and progress monitoring (227). Text messaging interventions can range from one-way reminders and tips to two-way communication for real-time interaction with lifestyle coaches (228). Some programs integrate multiple digital formats to enhance engagement and deliver NDPP content (229). Overall, digital programs are increasingly recognized as effective, with meta-analyses showing a mean body weight loss of 4% of baseline weight (174,175). For example, the Omada Health program is a year-long digital program that begins with a 16-week intensive phase focused on weight loss, followed by 36 weeks of weight maintenance content. Participants use internet-enabled devices to complete weekly interactive lessons, exchange messages with a lifestyle coach, and interact with a virtual peer group. The program also supports self-monitoring through meal logging, wireless scales for weight tracking, and wearable devices for physical activity monitoring. In a randomized controlled trial involving 599 participants, those enrolled in Omada’s program, when compared to controls, achieved significantly greater weight loss (5.5% vs. 2.1%, p<0.001) and A1C change (-0.23% vs. -0.16%, p<0.001) (227). Another program offered by Noom uses a similar app-based approach, delivering a structured behavior change curriculum supported by health coaching and self-monitoring tools. In a retrospective cohort study of more than 35,000 users, 77.9% reported weight loss while using the app for a median of 267 days, and 22.7% reported achieving a reduction of more than 10% of their baseline body weight (230).

Although promising, technology-mediated interventions have not been studied as extensively as traditional face-to-face formats in real-world settings. Further research is needed to evaluate how these interventions can be effectively implemented and sustained across healthcare and community settings and potentially delivered at a population level. It is also critically important to ensure that the proliferation of digital platforms for NDPP delivery does not limit access to intensive lifestyle intervention services by high-risk individuals who face barriers to accessing or engaging fully in technology platforms (231,232). This includes addressing such barriers as digital literacy, disability, access to devices and internet, and ensuring cultural and contextual relevance in program design and delivery (233).

#### Tailoring Preventive Lifestyle Interventions to Reach Individuals With Differing Preferences and Abilities

Numerous initiatives have tested adaptations of the DPP to reach populations that have historically been underserved, face greater barriers to participation, or experience lower effectiveness. Examples include older adults, younger adults, rural communities, men, women with gestational diabetes, and several racial and ethnic minority groups, including African American (234), Hispanic/Latino (235), Native Hawaiian and Other Pacific Islander, Arab American, and American Indian and Alaska Native communities (234,235,236,237,238). Adaptations often involve delivering the program in community-based settings, modifying content to reflect cultural values (e.g., faith and dietary practices), simplifying materials to accommodate varying literacy levels, employing bilingual staff, and providing additional support services, such as gym memberships, transportation, and childcare. These strategies have the potential to improve the cultural relevance of intervention services to improve participation (or reach) by all high-risk populations, as well as effectiveness in supporting both behavioral change and weight loss (235).

Notable examples of culturally adapted programs include PreventT2 Together (239), which modifies the program for couples to enhance support and behavior change, and the PowerUp program, targeting underrepresented Black and Latino men in disadvantaged neighborhoods (240). Other adaptations focus on tailoring the NDPP for rural communities (241), adapting the program for older adults through telehealth interventions, such as BRIDGE (242), modifying it for younger populations via the PRIORITY program (243), testing it with women who have a history of gestational diabetes (244), and creating family-centered interventions that engage both children and adults (245), among others. These important studies provide additional answers for how more targeted intervention adaptations improve not only reach and representativeness but also effectiveness of DPP-like interventions.

#### Potential Precision Medicine Approaches in the Type 2 Diabetes Prevention Field

The dominant paradigm for offering evidence-based diabetes prevention interventions in U.S. clinical practice has been to identify high-risk individuals (i.e., based on any of the three metabolic tests that define prediabetes or, in the case of the NDPP, based only on an elevated risk score) and to begin by offering an intensive lifestyle intervention (e.g., referral linkage to enroll with an NDPP supplier). Clinical guidelines and USPSTF recommendations also encourage consideration of initial metformin therapy for those of advanced age or BMI ≥35 kg/m^2^ or for those who do not respond to initial lifestyle intervention therapy (6,197). Given the aforementioned barriers to metformin use for type 2 diabetes prevention in the United States, most patients who receive a preventive treatment recommendation receive nothing more than encouragement to engage in lifestyle interventions. Because lifestyle intervention access is often funded by third-party health payors that limit coverage to about 12 months for most patients, most adults who start lifestyle intervention services only receive them for a limited time, regardless of their response. This paradigm fails to consider individual patient characteristics at the time of initial treatment selection or when making decisions about subsequent therapeutic changes or the duration of therapy guided by treatment response. Overall, this strategy has reached less than 1% of the target population and effectiveness is largely unknown, although it is likely limited by low treatment persistence, dropout, and reversion to prior high-risk status after treatment removal.

Generally, when there is evidence for effectiveness and safety of multiple treatment alternatives, an alternative implementation strategy is to customize treatment decisions based on individual characteristics (e.g., biometric, metabolic, or genetic signatures, as well as patient preference) and response to therapy (e.g., evidence for ongoing treatment use, weight loss, or changes in metabolic test results in response to treatment). This adds implementation complexity but has potential to improve both treatment engagement and response. Diabetes prevention interventions have differing likely mechanisms of action that include weight loss (e.g., bariatric surgery, metabolic medications, and intensive lifestyle interventions), enhanced glucose-dependent insulin secretion (e.g., GLP-1 receptor agonists), reduced hepatic glucose production (e.g., metformin), improved insulin sensitivity and glucose uptake by myocytes (e.g., regular physical activity), and improved sensitivity to insulin by adipocytes and muscle (e.g., thiazolidinediones). In this context, the initial therapy for someone with severe obesity might instead prioritize bariatric surgery or GLP-1-based treatments; for those with IGT, it might preference intensive lifestyle interventions, physical activity, or weight loss pharmacotherapy; for those with IFG, it might include metformin; and for those with high fasting triglyceridemia and steatosis or other evidence of centripetal (visceral) adiposity, it might prioritize intensive lifestyle interventions, bariatric procedures or medication, or consideration of thiazolidinediones.

Patient preference is also critical to engagement in initial treatment (221). Patients who are motivated to avoid or postpone the need to take additional medications are unlikely to engage with or benefit from a medication-based preventive strategy; those with weight loss failure expectations or barriers that interfere with their participation in behavioral coaching services are less likely to benefit from a NDPP referral linkage; and those motivated primarily to lose weight may best be suited to consider a bariatric medication, surgery, or intensive lifestyle intervention, rather than a thiazolidinedione or other treatment that yields very little weight change. Interventions that invest additional time in shared treatment decision-making improve initial treatment acceptance and engagement, but other forms of therapeutic customization for diabetes prevention demand further study.

Clinical efficacy trials already provide considerable information about heterogeneity of treatment effects for diabetes prevention that take two different forms: effect modification (i.e., different treatment benefits and harms for different patient subgroups) and an average trend towards larger relative risk reductions among subjects with the greatest baseline risk for developing type 2 diabetes (246,247). The DPP findings of differences in hazard reduction associated with metformin treatment for participants with higher BMI, older age, or a history of gestational diabetes are examples of effective modification (51,248). DPP data also demonstrated that baseline participant characteristics beyond baseline glycemic severity alone could predict absolute risk of developing type 2 diabetes during the trial (249). This study showed that lifestyle intervention treatment produced similar hazard ratios (i.e., relative risk reduction) regardless of baseline type 2 diabetes risk, such that those with the highest absolute risk experienced the largest absolute risk reduction and lowest number needed to treat to prevent one case of type 2 diabetes. Conversely, the hazard ratio for metformin varied considerably by baseline type 2 diabetes risk, such that most of the effect observed in that treatment arm was driven by the risk reduction among participants in the highest quartile of baseline diabetes risk. Such a model could be useful in focusing clinical treatment selection towards lifestyle-based treatments and away from metformin for individuals with lower baseline risk. Notably, although waist circumference and serum triglyceride concentration were also significant in the model, the main drivers of the risk prediction were the baseline fasting glucose or A1C severity (2-hour glucose was not included because it is generally not available clinically), so an even simpler stratification might be to offer metformin therapy only among individuals with higher levels of fasting glucose or A1C.

These findings were replicated in a second study using DPP data that also considered treatment adherence as a moderating variable of the hazard reduction in type 2 diabetes with each treatment arm (250). Adherence, per se, was defined at the 6-month visit for the metformin arm as taking 80% or more of assigned medication and for the lifestyle arm as having achieved a weight loss ≥5% of baseline weight. Compared with the earlier study, this study also omitted from the risk prediction models baseline variables for A1C and waist circumference, added variables for baseline history of gestational diabetes and polycystic ovarian disease, as well as physical activity minutes per week and smoking status, and modeled risk separately by DPP treatment arm, revealing additional patterns. Metformin again was observed to have little to no effect on reducing incident type 2 diabetes for those in the lowest two quartiles of baseline diabetes risk, regardless of whether treatment adherence was taken into consideration. Lifestyle treatment also significantly lowered the risk for type 2 diabetes across all levels of baseline risk, resulting in the largest absolute risk reductions for those in the highest quartile of baseline risk. When including the 38% of all participants who did not achieve ≥5% weight loss by 6 months, the overall hazard ratio associated with lifestyle treatment did not shrink significantly, even for those in the lowest quartiles of baseline risk. This finding suggests that removing lifestyle intervention support based only on 6-month weight loss progress would not be an evidence-based strategy. Interestingly, this study did find that participants who reported high baseline physical activity lost less weight and had a lower risk reduction when offered the lifestyle intervention, presumably because their overall change in behavior after starting the intervention was limited by their preexisting higher activity levels. This too could have some implications for initial treatment selection in clinical practice.

Genetic risk stratification represents another possible future approach for targeting those most likely to benefit from treatment to prevent type 2 diabetes. The DPP research group estimated a genetic risk score in participants randomized to the lifestyle arm, which was based on 67 single nucleotide polymorphisms that are associated with type 2 diabetes. This post-hoc analysis reported a dose-response relationship whereby adherent participants experienced incrementally greater benefit from the intensive lifestyle intervention as their genetic risk score increased (251). Another genetic study using DPP data found that neither the DPP lifestyle intervention nor metformin were effective among participants with a polygenic profile that indicated ß-cell decline (252). Therefore, individuals with this genetic profile should likely not be offered either of these evidence-based treatments since they are unlikely to derive benefit. To our knowledge, there have been no similar studies exploring whether those same patients would benefit from bariatric surgery or a GLP-1-based medication alternative. While these studies represent advances towards informing more of a “precision medicine” approach for type 2 diabetes prevention, the use of similar genetic data is not currently available in real-world practice settings. Future studies are needed to guide the implementation of such genetic profiling in primary care clinics and other settings where DPP lifestyle interventions and metformin are offered to high-risk adults.

## Conclusions

The past 30 years have seen the dawn of a new field of science focusing on the primary prevention of type 2 diabetes, primarily targeting high-risk adults who are identified with a glycemic test result just below thresholds for diagnosing and treating type 2 diabetes. Rigorous clinical trials spanning multiple continents demonstrated consistent, strong effects of intensive lifestyle behavioral interventions and, to a somewhat lesser extent, select medications to prevent or delay progression to type 2 diabetes. The feasibility and sustainability of offering these evidence-based treatments in routine clinical and community practice settings have proved challenging and remain an active area of translational and implementation science. The dominant existing implementation approach emphasizing referral linkages to lower-intensity and time-bound adaptations of clinical trial lifestyle interventions likely has benefits for the nearly 1 million U.S. adults with high-risk characteristics, but the strategy has identified and engaged <1% of roughly 100 million adults currently living with prediabetes so is unlikely to be achieving population-level effects on slowing type 2 diabetes incidence. Further research is needed to improve implementation and effectiveness on a large scale. Existing research also supports that for those who do engage in treatment, individual intervention strategies have an important role in preventing or delaying the need for initiating type 2 diabetes treatment; however, it is unclear whether such strategies prevent long-term complications in ways already shown following intensive monitoring and glucose-lowering management among those who have progressed to more severe metabolic abnormalities and a diagnosis of type 2 diabetes (14). In this context, it remains of critical importance to maintain focus on the prompt identification and intensive management of incident type 2 diabetes.

Because preventive interventions that target high-risk individuals require blood tests to identify prediabetes, prescription medications or bariatric procedures that must be delivered by clinical professionals, and relatively high ongoing costs that benefit from third-party health payors, the structure and process of U.S. healthcare systems can both facilitate and impede efforts to bring evidence-based type 2 diabetes prevention to more individuals. Hospitals and physicians’ offices are largely not resourced for efficient and effective lifestyle intervention delivery, and the outsourcing of those treatments by referral linkages to NDPP suppliers adds complexity and makes the monitoring of treatment responses and care continuity more difficult. Integration and coordination of these activities are likely to improve implementation success. As an example, early evidence from the National Health Service—England’s single-payor, government-supported insurance plan—demonstrated large enrollment in its Diabetes Prevention Programme with weight loss and A1C reductions that were comparable with much smaller translational trials in the United States (253).

Administrative barriers also impact other effective forms of intervention for diabetes prevention. No medications currently have FDA approval for the indication of type 2 diabetes prevention, and although several FDA-approved weight loss pharmacotherapies are also effective in diabetes prevention, costs are high and reimbursement for obesity pharmacotherapy by commercial health plans and public programs is inconsistent or often time bound. These challenges have undoubtedly slowed efforts by the research, clinical, and public health communities to bring these beneficial therapies to millions of American adults at high risk for type 2 diabetes today.

Over the past 15 years, research has informed and advanced important practice and policy changes in areas of prediabetes screening, the adoption, implementation, and scaling of lifestyle intervention programs adapted from the DPP, NDPP infrastructure led by the CDC, and policies by Medicare, Medicaid, and commercial third-party health payors to cover the delivery costs of high-fidelity, DPP-like intervention programs on behalf of high-risk adults. These efforts represent one of the most striking examples of the power of stakeholder-engaged translational research to inform practice and policy. The NDPP may be the only preventive behavioral intervention in the United States that has been successfully translated into real-world practice and covered by health insurance reimbursement. Despite these remarkable achievements that stemmed from the field of type 2 diabetes prevention and science reviewed here, multiple gaps persist today, warranting further research and policy action.

Diabetes prevention interventions are recommended for nearly 98 million U.S. adults living with prediabetes. As of April 2025, about 819,000 people (less than 1%) have enrolled in an evidence-based lifestyle intervention recognized by the NDPP (170); and a comparable proportion have taken a medication for type 2 diabetes prevention. Key determinants of this overall “low reach” include: (1.) low awareness and adoption of clinical practice recommendations for prediabetes screening and management by the healthcare community; (2.) inconsistent or ineffective approaches for educating, motivating, and preparing high-risk adults to complete screening and engage in available interventions; and (3.) limitations of the current design and delivery of DPP-like interventions to ensure they are engaging, culturally relevant, and effective across highly diverse individuals and communities of American adults. Further research and action are needed to overcome these and additional challenges. On a national level, administrative efficiencies can also be gained through improved coordination of MDPP and NDPP eligibility and reporting requirements (183), as well as from health system screening, seamless e-referral, and quality-monitoring systems (209), that create shared incentives and accountability while minimizing additional demands on busy professionals and administrative staff. If capacity constraints continue to impede focused efforts to deliver treatment to those high-risk individuals most likely to benefit, then narrower definitions of the target population using risk models or simply targeting those with higher baseline A1C or FPG levels may help to reach those most likely to benefit from intensive lifestyle interventions, as well as metformin. Finally, although GLP-1 receptor agonists continue to accumulate evidence as potentially powerful agents for type 2 diabetes primary prevention, they are less appropriate for the large segment of adults with prediabetes who have normal or only slightly overweight BMI, as well as many individuals motivated to avoid medication-based therapies; they also have high costs that currently are inconsistently reimbursed by U.S. health insurance and have a high rate of discontinuation. Additional research will be needed to establish their future role in the spectrum of diabetes prevention intervention alternatives. Closing each of these gaps will require ongoing collaboration, research, and practice change.

## List of Abbreviations

A1C: glycated hemoglobin
ACA: Affordable Care Act
ADA: American Diabetes Association
BMI: body mass index
CDC: U.S. Centers for Disease Control and Prevention
CMS: U.S. Centers for Medicare and Medicaid Services
DPP: U.S. Diabetes Prevention Program
FDA: U.S. Food and Drug Administration
FPG: fasting plasma glucose
GIP: glucose-dependent insulinotropic polypeptide
GLP-1: glucagon-like peptide-1
IFG: impaired fasting glucose
IGT: impaired glucose tolerance
IQR: interquartile range
MDPP: Medicare Diabetes Prevention Program
NDPP: National Diabetes Prevention Program
NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases
OGTT: oral glucose tolerance test
SGLT2: sodium-glucose cotransporter-2
USPSTF: United States Preventive Services Task Force

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Glucose: mg/dL x 0.0555 = mmol/L

## Funding

TF was supported by a T32 fellowship training grant from the NIH National Heart, Lung, and Blood Institute (T32HL079891). RTA and MJO were supported by the Chicago Center for Diabetes Translation Research (P30-DK092949). KSD was supported by the National Institute of General Medical Science (P20GM109036).

## Acknowledgment

This is an update of: Knowler WC, Crandall JP, Chiasson JL, et al. Prevention of Type 2 Diabetes. Chapter 38 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 38.1–38.21.

The authors gratefully acknowledge Maria Vargas, MPH, for her role in management of references and preparation of the manuscript.

## Article History

Received in final form on August 21, 2025.

## References

1 Knowler WC, Crandall JP, Chiasson J-L, Nathan DM. Prevention of type 2 diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America, 3rd Edition. National Institutes of Health 2018; 38.1-38.21:chap 38. https://www.ncbi.nlm.nih.gov/books/NBK567982/
2 Geiss LS, Wang J, Cheng YJ, et al. Prevalence and incidence trends for diagnosed diabetes among adults aged 20 to 79 years, United States, 1980–2012. JAMA. 2014;312(12):1218-1226. doi:10.1001/jama.2014.11494 25247518
3 U.S. Centers for Disease Control and Prevention (CDC). National Diabetes Statistics Report. National Center for Health Statistics, U.S. Centers for Disease Control and Prevention. U.S. Department of Health and Human Services. 2024. Accessed May 5, 2025. https://www.cdc.gov/diabetes/php/data-research/index.html
4 Redondo MJ, Balasubramanyam A. Toward an improved classification of type 2 diabetes: lessons from research into the heterogeneity of a complex disease. J Clin Endocrinol Metab. 2021;106(12):e4822-e4833. doi:10.1210/clinem/dgab545 34291809
5 Stone SI, Balasubramanyam A, Posey JE. Atypical diabetes: What have we learned and what does the future hold? Diabetes Care. 2024;47(5):770-781. doi:10.2337/dci23-0038 38329838
6 American Diabetes Association (ADA) Professional Practice Committee. 3. Prevention or Delay of Diabetes and Associated Comorbidities: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S50-S58. doi:10.2337/dc25-S003 39651971
7 Fazakerley DJ, Krycer JR, Kearney AL, Hocking SL, James DE. Muscle and adipose tissue insulin resistance: malady without mechanism? J Lipid Res. 2019;60(10):1720-1732. doi:10.1194/jlr.R087510 30054342
8 Lee SH, Park SY, Choi CS. Insulin resistance: from mechanisms to therapeutic strategies. Diabetes Metab J. 2022;46(1):15-37. doi:10.4093/dmj.2021.0280 34965646
9 Santoro A, McGraw TE, Kahn BB. Insulin action in adipocytes, adipose remodeling, and systemic effects. Cell Metab. 2021;33(4):748-757. doi:10.1016/j.cmet.2021.03.019 33826917
10 Nathan DM, Davidson MB, DeFronzo RA, et al. Impaired fasting glucose and impaired glucose tolerance: implications for care. Diabetes Care. 2007;30(3):753-759. doi:10.2337/dc07-9920 17327355
11 DeFronzo RA, Eldor R, Abdul-Ghani M. Pathophysiologic approach to therapy in patients with newly diagnosed type 2 diabetes. Diabetes Care. 2013;36(Suppl 2):S127-S138. doi:10.2337/dcS13-2011 23882037
12 American Diabetes Association (ADA) Professional Practice Committee. 2. Diagnosis and Classification of Diabetes: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S27-S49. doi:10.2337/dc25-S002 39651986
13 American Diabetes Association (ADA) Professional Practice Committee. 9. Pharmacologic Approaches to Glycemic Treatment: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(Suppl 1):S181-S206. doi:10.2337/dc25-S009 39651989
14 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA. 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med. 2008;359(15):1577-1589. doi:10.1056/NEJMoa0806470 18784090
15 Huang ES, Shook M, Jin L, Chin MH, Meltzer DO. The impact of patient preferences on the cost-effectiveness of intensive glucose control in older patients with new-onset diabetes. Diabetes Care. 2006;29(2):259-264. doi:10.2337/diacare.29.02.06.dc05-1443 16443870
16 Johnson FR, Manjunath R, Mansfield CA, Clayton LJ, Hoerger TJ, Zhang P. High-risk individuals’ willingness to pay for diabetes risk-reduction programs. Diabetes Care. 2006;29(6):1351-1356. doi:10.2337/dc05-2221 16732020
17 U.S. Centers for Disease Control and Prevention (CDC). United States Diabetes Surveillance System. Centers for Disease Control and Prevention, U.S. Department of Health and Human Services. 2025. Accessed June 19, 2025. https://gis.cdc.gov/grasp/diabetes/DiabetesAtlas.html
18 Rose G. Sick individuals and sick populations. Int J Epidemiol. 1985;14(1):32-38. doi:10.1093/ije/14.1.32 3872850
19 Mudaliar S. The evolution of diabetes treatment through the ages: from starvation diets to insulin, incretins, SGLT2-inhibitors and beyond. J Indian Inst Sci. 2023;103:1-11. doi:10.1007/s41745-023-00357-w 36845885
20 Opazo-Díaz E, Montes-de-Oca-García A, Gálan-Mercant A, Marín-Galindo A, Corral-Pérez J, Ponce-González JG. Characteristics of high-intensity interval training influence anthropometrics, glycemic control, and cardiorespiratory fitness in type 2 diabetes mellitus: a systematic review and meta-analysis of randomized controlled trials. Sports Med. 2024;54(12):3127-3149. doi:10.1007/s40279-024-02114-0 39358495
21 Silva FM, Duarte-Mendes P, Teixeira AM, Soares CM, Ferreira JP. The effects of combined exercise training on glucose metabolism and inflammatory markers in sedentary adults: a systematic review and meta-analysis. Sci Rep. 2024;14(1):1936. doi:10.1038/s41598-024-51832-y 38253590
22 Kanbour S, Ageeb RA, Malik RA, Abu-Raddad LJ. Impact of bodyweight loss on type 2 diabetes remission: a systematic review and meta-regression analysis of randomised controlled trials. Lancet Diabetes Endocrinol. 2025;13(4):294-306. doi:10.1016/S2213-8587(24)00346-2 40023186
23 Kisling LA, Das JM. Prevention strategies. In: StatPearls [Internet]. StatPearls Publishing; 2025. https://www.ncbi.nlm.nih.gov/books/NBK537222/
24 Gregg EW, Cadwell BL, Cheng YJ, et al. Trends in the prevalence and ratio of diagnosed to undiagnosed diabetes according to obesity levels in the U.S. Diabetes Care. 2004;27(12):2806-2812. doi:10.2337/diacare.27.12.2806 15562189
25 Amico A, Wootan MG, Jacobson MF, Leung C, Willett AW. The demise of artificial trans fat: a history of a public health achievement. Milbank Q. 2021;99(3):746-770. doi:10.1111/1468-0009.12515 34342900
26 Zhang Y, Koene M, Reijneveld SA, et al. The impact of interventions in the built environment on physical activity levels: a systematic umbrella review. Int J Behav Nutr Phys Act. 2022;19(1):156. doi:10.1186/s12966-022-01399-6 36550583
27 Hagenaars LL, Jeurissen PPT, Klazinga NS, Listl S, Jevdjevic M. Effectiveness and policy determinants of sugar-sweetened beverage taxes. J Dent Res. 2021;100(13):1444-1451. doi:10.1177/00220345211014463 34034538
28 White JS, Basu S, Kaplan S, Madsen KA, Villas-Boas SB, Schillinger D. Evaluation of the sugar-sweetened beverage tax in Oakland, United States, 2015–2019: a quasi-experimental and cost-effectiveness study. PLoS Med. 2023;20(4):e1004212. doi:10.1371/journal.pmed.1004212 37071600
29 Jia J, Van Horn L, Linder JA, Ackermann RT, Kandula NR, O’Brien MJ. Menu calorie label use and diet quality: a cross-sectional study. Am J Prev Med. 2023;65(6):1069-1077. doi:10.1016/j.amepre.2023.07.003 37433378
30 Rajagopalan S, Brook RD, Salerno P, et al. Air pollution exposure and cardiometabolic risk. Lancet Diabetes Endocrinol. 2024;12(3):196-208. doi:10.1016/S2213-8587(23)00361-3 38310921
31 Lind PM, Lind L. Endocrine-disrupting chemicals and risk of diabetes: an evidence-based review. Diabetologia. 2018;61(7):1495-1502. doi:10.1007/s00125-018-4621-3 29744538
32 Ludwig J, Sanbonmatsu L, Gennetian L, et al. Neighborhoods, obesity, and diabetes—a randomized social experiment. N Engl J Med. 2011;365(16):1509-1519. doi:10.1056/NEJMsa1103216 22010917
33 Chriqui JF, Sansone CN, Powell LM. The sweetened beverage tax in Cook County, Illinois: lessons from a failed effort. Am J Public Health. 2020;110(7):1009-1016. doi:10.2105/AJPH.2020.305640 32437287
34 Eykelenboom M, van Stralen MM, Olthof MR, et al. Political and public acceptability of a sugar-sweetened beverages tax: a mixed-method systematic review and meta-analysis. Int J Behav Nutr Phys Act. 2019;16(1):78. doi:10.1186/s12966-019-0843-0 31484538
35 Steele L, Drummond E, Nishida C, et al. Ending Trans Fat—the first-ever global elimination program for a noncommunicable disease risk factor: JACC International. J Am Coll Cardiol. 2024;84(7):663-674. doi:10.1016/j.jacc.2024.04.067 39111974
36 Ding L, Fan Y, Li H, et al. Comparative effectiveness of bariatric surgeries in patients with obesity and type 2 diabetes mellitus: a network meta-analysis of randomized controlled trials. Obes Rev. 2020;21(8):e13030. doi:10.1111/obr.13030 32286011
37 Tsilingiris D, Koliaki C, Kokkinos A. Remission of type 2 diabetes mellitus after bariatric surgery: fact or fiction? Int J Environ Res Public Health. 2019;16(17):3171. doi:10.3390/ijerph16173171 31480306
38 Batterham RL, Cummings DE. Mechanisms of diabetes improvement following bariatric/metabolic surgery. Diabetes Care. 2016;39(6):893-901. doi:10.2337/dc16-0145 27222547
39 Venditti EM, Kramer MK. Necessary components for lifestyle modification interventions to reduce diabetes risk. Curr Diab Rep. 2012;12(2):138-146. doi:10.1007/s11892-012-0256-9 22350807
40 Bird SR, Hawley JA. Update on the effects of physical activity on insulin sensitivity in humans. BMJ Open Sport Exerc Med. 2017;2(1):e000143. doi:10.1136/bmjsem-2016-000143 28879026
41 GoodRx Inc. GoodRx. 2025. Accessed July 5, 2025. https://www.goodrx.com/
42 Li R, Qu S, Zhang P, et al. Economic evaluation of combined diet and physical activity promotion programs to prevent type 2 diabetes among persons at increased risk: a systematic review for the Community Preventive Services Task Force. Ann Intern Med. 2015;163(6):452-460. doi:10.7326/M15-0469 26167962
43 Kanat M, Mari A, Norton L, et al. Distinct beta-cell defects in impaired fasting glucose and impaired glucose tolerance. Diabetes. 2012;61(2):447-453. doi:10.2337/db11-0995 22275086
44 Marini MA, Frontoni S, Succurro E, et al. Insulin sensitivity, and beta-cell function in relation to hemoglobin A1C. Nutr Metab Cardiovasc Dis. 2014;24(1):27-33. doi:10.1016/j.numecd.2013.01.011 23601331
45 Cohen RM, Franco RS, Khera PK, et al. Red cell life span heterogeneity in hematologically normal people is sufficient to alter HbA1c. Blood. 2008;112(10):4284-4291. doi:10.1182/blood-2008-04-154112 18694998
46 Shrestha RP, Horowitz J, Hollot CV, et al. Models for the red blood cell lifespan. J Pharmacokinet Pharmacodyn. 2016;43(3):259-274. doi:10.1007/s10928-016-9470-4 27039311
47 James C, Bullard KM, Rolka DB, et al. Implications of alternative definitions of prediabetes for prevalence in U.S. adults. Diabetes Care. 2011;34(2):387-391. doi:10.2337/dc10-1314 21270196
48 Zhang HJ, Tan X, Wang NJ. National trends in insulin resistance and beta-cell dysfunction among adults with prediabetes: NHANES 2001–2016. Chronic Dis Transl Med. 2021;7(2):125-134. doi:10.1016/j.cdtm.2020.11.003 34136772
49 Pan XR, Li GW, Hu YH, et al. Effects of diet and exercise in preventing NIDDM in people with impaired glucose tolerance. The Da Qing IGT and Diabetes Study. Diabetes Care. 1997;20(4):537-544. doi:10.2337/diacare.20.4.537 9096977
50 Tuomilehto J, Lindström J, Eriksson JG, et al. Prevention of type 2 diabetes mellitus by changes in lifestyle among subjects with impaired glucose tolerance. N Engl J Med. 2001;344(18):1343-1350. doi:10.1056/NEJM200105033441801 11333990
51 Knowler WC, Barrett-Connor E, Fowler SE, et al. Reduction in the incidence of type 2 diabetes with lifestyle intervention or metformin. N Engl J Med. 2002;346(6):393-403. doi:10.1056/NEJMoa012512 11832527
52 Li G, Zhang P, Wang J, et al. The long-term effect of lifestyle interventions to prevent diabetes in the China Da Qing Diabetes Prevention Study: a 20-year follow-up study. Lancet. 2008;371(9626):1783-1789. doi:10.1016/S0140-6736(08)60766-7 18502303
53 Diabetes Prevention Program (DPP) Research Group. Long-term effects of lifestyle intervention or metformin on diabetes development and microvascular complications over 15-year follow-up: the Diabetes Prevention Program Outcomes Study. Lancet Diabetes Endocrinol. 2015;3(11):866-875. doi:10.1016/S2213-8587(15)00291-0 26377054
54 Nathan DM, Bennett PH, Crandall JP, et al. Does diabetes prevention translate into reduced long-term vascular complications of diabetes? Diabetologia. 2019;62(8):1319-1328. doi:10.1007/s00125-019-4928-8 31270584
55 Goldberg RB, Orchard TJ, Crandall JP, et al. Effects of long-term metformin and lifestyle interventions on cardiovascular events in the Diabetes Prevention Program and its Outcome Study. Circulation. 2022;145(22):1632-1641. doi:10.1161/CIRCULATIONAHA.121.056756 35603600
56 Hamman RF, Wing RR, Edelstein SL, et al. Effect of weight loss with lifestyle intervention on risk of diabetes. Diabetes Care. 2006;29(9):2102-2107. doi:10.2337/dc06-0560 16936160
57 Diabetes Prevention Program (DPP) Research Group. The Diabetes Prevention Program. Design and methods for a clinical trial in the prevention of type 2 diabetes. Diabetes Care. 1999;22(4):623-634. doi:10.2337/diacare.22.4.623 10189543
58 Eriksson J, Lindström J, Valle T, et al. Prevention of type II diabetes in subjects with impaired glucose tolerance: the Diabetes Prevention Study (DPS) in Finland. Study design and 1-year interim report on the feasibility of the lifestyle intervention programme. Diabetologia. 1999;42(7):793-801. doi:10.1007/s001250051229 10440120
59 Centre for Effective Services (CES). CES Guide to Implementation. The Centre for Effective Services (CES). 2022. Accessed September 12, 2024. https://implementation.effectiveservices.org/
60 Kirchner JE, Smith JL, Powell BJ, Waltz TJ, Proctor EK. Getting a clinical innovation into practice: an introduction to implementation strategies. Psychiatry Res. 2020;283:112467. doi:10.1016/j.psychres.2019.06.042 31488332
61 Dhali B, Chatterjee S, Sundar Das S, Cruz MD. Effect of yoga and walking on glycemic control for the management of type 2 diabetes: a systematic review and meta-analysis. J ASEAN Fed Endocr Soc. 2023;38(2):113-122. doi:10.15605/jafes.038.02.20 38045671
62 Kriska AM, Rockette-Wagner B, Edelstein SL, et al. The impact of physical activity on the prevention of type 2 diabetes: evidence and lessons learned from the Diabetes Prevention Program, a long-standing clinical trial incorporating subjective and objective activity measures. Diabetes Care. 2021;44(1):43-49. doi:10.2337/dc20-1129 33444158
63 Laaksonen DE, Lindström J, Lakka TA, et al. Physical activity in the prevention of type 2 diabetes: the Finnish Diabetes Prevention Study. Diabetes. 2005;54(1):158-165. doi:10.2337/diabetes.54.1.158 15616024
64 Dai X, Zhai L, Chen Q, et al. Two-year-supervised resistance training prevented diabetes incidence in people with prediabetes: a randomised control trial. Diabetes Metab Res Rev. 2019;35(5):e3143. doi:10.1002/dmrr.3143 30768758
65 Ge L, Sadeghirad B, Ball GDC, et al. Comparison of dietary macronutrient patterns of 14 popular named dietary programmes for weight and cardiovascular risk factor reduction in adults: systematic review and network meta-analysis of randomised trials. BMJ. 2020;369:m696. doi:10.1136/bmj.m696 32238384
66 Diabetes Prevention Program (DPP) Research Group. The Diabetes Prevention Program (DPP): description of lifestyle intervention. Diabetes Care. 2002;25(12):2165-2171. doi:10.2337/diacare.25.12.2165 12453955
67 Salas-Salvadó J, Bulló M, Babio N, et al. Reduction in the incidence of type 2 diabetes with the Mediterranean diet: results of the PREDIMED-Reus nutrition intervention randomized trial. Diabetes Care. 2011;34(1):14-19. doi:10.2337/dc10-1288 20929998
68 Bloomfield HE, Koeller E, Greer N, MacDonald R, Kane R, Wilt TJ. Effects on health outcomes of a Mediterranean diet with no restriction on fat intake: a systematic review and meta-analysis. Ann Intern Med. 2016;165(7):491-500. doi:10.7326/M16-0361 27428849
69 Stentz FB, Brewer A, Wan J, et al. Remission of pre-diabetes to normal glucose tolerance in obese adults with high protein versus high carbohydrate diet: randomized control trial. BMJ Open Diabetes Res Care. 2016;4(1):e000258. doi:10.1136/bmjdrc-2016-000258 27843552
70 Evert AB, Dennison M, Gardner CD, et al. Nutrition Therapy for Adults With Diabetes or Prediabetes: A Consensus Report. Diabetes Care. 2019;42(5):731-754. doi:10.2337/dci19-0014 31000505
71 Termannsen AD, Søndergaard CS, Færch K, Andersen TH, Raben A, Quist JS. Effects of plant-based diets on markers of insulin sensitivity: a systematic review and meta-analysis of randomised controlled trials. Nutrients. 2024;16(13):2110. doi:10.3390/nu16132110 38999858
72 Zhu Y, Zheng Q, Huang L, et al. The effects of plant-based dietary patterns on the risk of developing gestational diabetes mellitus: a systematic review and meta-analysis. PLoS One. 2023;18(10):e0291732. doi:10.1371/journal.pone.0291732 37792722
73 Stentz FB, Mikhael A, Kineish O, Christman J, Sands C. High protein diet leads to prediabetes remission and positive changes in incretins and cardiovascular risk factors. Nutr Metab Cardiovasc Dis. 2021;31(4):1227-1237. doi:10.1016/j.numecd.2020.11.027 33549435
74 Dorans KS, Bazzano LA, Qi L, et al. Effects of a low-carbohydrate dietary intervention on hemoglobin A1c: a randomized clinical trial. JAMA Netw Open. 2022;5(10):e2238645. doi:10.1001/jamanetworkopen.2022.38645 36287562
75 Gardner CD, Landry MJ, Perelman D, et al. Effect of a ketogenic diet versus Mediterranean diet on glycated hemoglobin in individuals with prediabetes and type 2 diabetes mellitus: the interventional Keto-Med randomized crossover trial. Am J Clin Nutr. 2022;116(3):640-652. doi:10.1093/ajcn/nqac154 35641199
76 Jeffery RW, Wing RR, Mayer RR. Are smaller weight losses or more achievable weight loss goals better in the long term for obese patients? J Consult Clin Psychol. 1998;66(4):641-645. doi:10.1037//0022-006x.66.4.641 9735580
77 Tronieri JS, Alamuddin N, Wadden TA. Behavioral approaches to obesity management. In: Feingold KR, Ahmed SF, Anawalt B, et al, eds. Endotext [Internet]. MDText.com; 2000. https://www.ncbi.nlm.nih.gov/books/NBK278952/
78 Dutta S, Shah RB, Singhal S, et al. Metformin: a review of potential mechanism and therapeutic utility beyond diabetes. Drug Des Devel Ther. 2023;17:1907-1932. doi:10.2147/DDDT.S409373 37397787
79 Walker EA, Molitch M, Kramer MK, et al. Adherence to preventive medications: predictors and outcomes in the Diabetes Prevention Program. Diabetes Care. 2006;29(9):1997-2002. doi:10.2337/dc06-0454 16936143
80 Ratner RE, Christophi CA, Metzger BE, et al. Prevention of diabetes in women with a history of gestational diabetes: effects of metformin and lifestyle interventions. J Clin Endocrinol Metab. 2008;93(12):4774-4779. doi:10.1210/jc.2008-0772 18826999
81 Nathan DM. Diabetes: advances in diagnosis and treatment. JAMA. 2015;314(10):1052-1062. doi:10.1001/jama.2015.9536 26348754
82 Knowler WC, Fowler SE, Hamman RF, et al. 10-year follow-up of diabetes incidence and weight loss in the Diabetes Prevention Program Outcomes Study. Lancet. 2009;374(9702):1677-1686. doi:10.1016/S0140-6736(09)61457-4 19878986
83 Ramachandran A, Snehalatha C, Mary S, et al. The Indian Diabetes Prevention Programme shows that lifestyle modification and metformin prevent type 2 diabetes in Asian Indian subjects with impaired glucose tolerance (IDPP-1). Diabetologia. 2006;49(2):289-297. doi:10.1007/s00125-005-0097-z 16391903
84 Moin T, Schmittdiel JA, Flory JH, et al. Review of metformin use for type 2 diabetes prevention. Am J Prev Med. 2018;55(4):565-574. doi:10.1016/j.amepre.2018.04.038 30126667
85 Chiasson J-L, Josse RG, Gomis R, et al. Acarbose for prevention of type 2 diabetes mellitus: the STOP-NIDDM randomised trial. Lancet. 2002;359(9323):2072-2077. doi:10.1016/S0140-6736(02)08905-5 12086760
86 Knowler WC, Hamman RF, Edelstein SL, et al. Prevention of type 2 diabetes with troglitazone in the Diabetes Prevention Program. Diabetes. 2005;54(4):1150-1156. doi:10.2337/diabetes.54.4.1150 15793255
87 Zinman B, Harris SB, Neuman J, et al. Low-dose combination therapy with rosiglitazone and metformin to prevent type 2 diabetes mellitus (CANOE trial): a double-blind randomised controlled study. Lancet. 2010;376(9735):103-111. doi:10.1016/S0140-6736(10)60746-5 20605202
88 Ipsen EØ, Madsen KS, Chi Y, et al. Pioglitazone for prevention or delay of type 2 diabetes mellitus and its associated complications in people at risk for the development of type 2 diabetes mellitus. Cochrane Database Syst Rev. 2020;11(11):CD013516. doi:10.1002/14651858.CD013516.pub2 33210751
89 Hemmingsen B, Sonne DP, Metzendorf MI, Richter B. Insulin secretagogues for prevention or delay of type 2 diabetes mellitus and its associated complications in persons at increased risk for the development of type 2 diabetes mellitus. Cochrane Database Syst Rev. 2016;10(10):CD012151. doi:10.1002/14651858.CD012151.pub2 27749986
90 Califf RM, Boolell M, Haffner SM, et al. Prevention of diabetes and cardiovascular disease in patients with impaired glucose tolerance: rationale and design of the Nateglinide And Valsartan in Impaired Glucose Tolerance Outcomes Research (NAVIGATOR) Trial. Am Heart J. 2008;156(4):623-632. doi:10.1016/j.ahj.2008.05.017 18946890
91 Naidoo P, Wing J, Rambiritch V. Effect of sitagliptin and metformin on prediabetes progression to type 2 diabetes—a randomized, double-blind, double-arm, multicenter clinical trial: protocol for the Sitagliptin and Metformin in PreDiabetes (SiMePreD) Study. JMIR Res Protoc. 2016;5(3):e145. doi:10.2196/resprot.5073 27491324
92 Hemmingsen B, Sonne DP, Metzendorf MI, Richter B. Dipeptidyl-peptidase (DPP)-4 inhibitors and glucagon-like peptide (GLP)-1 analogues for prevention or delay of type 2 diabetes mellitus and its associated complications in people at increased risk for the development of type 2 diabetes mellitus. Cochrane Database Syst Rev. 2017;5(5):CD012204. doi:10.1002/14651858.CD012204.pub2 28489279
93 le Roux CW, Astrup A, Fujioka K, et al. 3 years of liraglutide versus placebo for type 2 diabetes risk reduction and weight management in individuals with prediabetes: a randomised, double-blind trial. Lancet. 2017;389(10077):1399-1409. doi:10.1016/S0140-6736(17)30069-7 28237263
94 Kahn SE, Deanfield JE, Jeppesen OK, et al. Effect of semaglutide on regression and progression of glycemia in people with overweight or obesity but without diabetes in the SELECT trial. Diabetes Care. 2024;47(8):1350-1359. doi:10.2337/dc24-0491 38907683
95 Jastreboff AM, le Roux CW, Stefanski A, et al. Tirzepatide for obesity treatment and diabetes prevention. N Engl J Med. 2025;392(10):958-971. doi:10.1056/NEJMoa2410819 39536238
96 Hemmingsen B, Krogh J, Metzendorf MI, Richter B. Sodium-glucose cotransporter (SGLT) 2 inhibitors for prevention or delay of type 2 diabetes mellitus and its associated complications in people at risk for the development of type 2 diabetes mellitus. Cochrane Database Syst Rev. 2016;4(4):CD012106. doi:10.1002/14651858.CD012106.pub2 27101360
97 Armato JP, DeFronzo RA, Abdul-Ghani M, Ruby RJ. Successful treatment of prediabetes in clinical practice using physiological assessment (STOP DIABETES). Lancet Diabetes Endocrinol. 2018;6(10):781-789. doi:10.1016/S2213-8587(18)30234-1 30224284
98 Elkind-Hirsch KE, Shaler D, Harris R. Postpartum treatment with liraglutide in combination with metformin versus metformin monotherapy to improve metabolic status and reduce body weight in overweight/obese women with recent gestational diabetes: a double-blind, randomized, placebo-controlled study. J Diabetes Complications. 2020;34(4):107548. doi:10.1016/j.jdiacomp.2020.107548 32046931
99 Pi-Sunyer X, Astrup A, Fujioka K, et al. A randomized, controlled trial of 3.0 mg of liraglutide in weight management. N Engl J Med. 2015;373(1):11-22. doi:10.1056/NEJMoa1411892 26132939
100 Wilding JPH, Batterham RL, Calanna S, et al. Once-weekly semaglutide in adults with overweight or obesity. N Engl J Med. 2021;384(11):989-1002. doi:10.1056/NEJMoa2032183 33567185
101 Jastreboff AM, Aronne LJ, Ahmad NN, et al. Tirzepatide once weekly for the treatment of obesity. N Engl J Med. 2022;387(3):205-216. doi:10.1056/NEJMoa2206038 35658024
102 McGowan BM, Bruun JM, Capehorn M, et al. Efficacy and safety of once-weekly semaglutide 2.4 mg versus placebo in people with obesity and prediabetes (STEP 10): a randomised, double-blind, placebo-controlled, multicentre phase 3 trial. Lancet Diabetes Endocrinol. 2024;12(9):631-642. doi:10.1016/S2213-8587(24)00182-7 39089293
103 Eli Lilly and Company. Tirzepatide reduced the risk of developing type 2 diabetes by 94% in adults with pre-diabetes and obesity or overweight. 2024. Accessed October 28, 2024. https://investor.lilly.com/news-releases/news-release-details/tirzepatide-reduced-risk-developing-type-2-diabetes-94-adults
104 Heymsfield SB, Segal KR, Hauptman J, et al. Effects of weight loss with orlistat on glucose tolerance and progression to type 2 diabetes in obese adults. Arch Intern Med. 2000;160(9):1321-1326. doi:10.1001/archinte.160.9.1321 10809036
105 Torgerson JS, Hauptman J, Boldrin MN, Sjöström L. XENical in the prevention of diabetes in obese subjects (XENDOS) study: a randomized study of orlistat as an adjunct to lifestyle changes for the prevention of type 2 diabetes in obese patients. Diabetes Care. 2004;27(1):155-161. doi:10.2337/diacare.27.1.155 14693982
106 Garvey WT, Ryan DH, Henry R, et al. Prevention of type 2 diabetes in subjects with prediabetes and metabolic syndrome treated with phentermine and topiramate extended release. Diabetes Care. 2014;37(4):912-921. doi:10.2337/dc13-1518 24103901
107 Gadde KM, Allison DB, Ryan DH, et al. Effects of low-dose, controlled-release, phentermine plus topiramate combination on weight and associated comorbidities in overweight and obese adults (CONQUER): a randomised, placebo-controlled, phase 3 trial. Lancet. 2011;377(9774):1341-1352. doi:10.1016/S0140-6736(11)60205-5 21481449
108 Apovian CM, Aronne L, Rubino D, et al. A randomized, phase 3 trial of naltrexone SR/bupropion SR on weight and obesity-related risk factors (COR-II). Obesity (Silver Spring). 2013;21(5):935-943. doi:10.1002/oby.20309 23408728
109 Diabetes Prevention Program (DPP) Research Group. Effects of withdrawal from metformin on the development of diabetes in the Diabetes Prevention Program. Diabetes Care. 2003;26(4):977-980. doi:10.2337/diacare.26.4.977 12663559
110 Gerstein HC, Bosch J, Dagenais GR, et al. Basal insulin and cardiovascular and other outcomes in dysglycemia. N Engl J Med. 2012;367(4):319-328. doi:10.1056/NEJMoa1203858 22686416
111 DREAM Trial Investigators. Incidence of diabetes following ramipril or rosiglitazone withdrawal. Diabetes Care. 2011;34(6):1265-1269. doi:10.2337/dc10-1567 21515846
112 Eriksson JG, Lehtovirta M, Ehrnström B, Salmela S, Groop L. Long-term beneficial effects of glipizide treatment on glucose tolerance in subjects with impaired glucose tolerance. J Intern Med. 2006;259(6):553-560. doi:10.1111/j.1365-2796.2006.01633.x 16704555
113 Haw JS, Galaviz KI, Straus AN, et al. Long-term sustainability of diabetes prevention approaches: a systematic review and meta-analysis of randomized clinical trials. JAMA Intern Med. 2017;177(12):1808-1817. doi:10.1001/jamainternmed.2017.6040 29114778
114 Fonseca VA, Capehorn MS, Garg SK, et al. Reductions in insulin resistance are mediated primarily via weight loss in subjects with type 2 diabetes on semaglutide. J Clin Endocrinol Metab. 2019;104(9):4078-4086. doi:10.1210/jc.2018-02685 30938762
115 Khorgami Z, Shoar S, Saber AA, Howard CA, Danaei G, Sclabas GM. Outcomes of bariatric surgery versus medical management for type 2 diabetes mellitus: a meta-analysis of randomized controlled trials. Obes Surg. 2019;29(3):964-974. doi:10.1007/s11695-018-3552-x 30402804
116 McTigue KM, Wellman R, Nauman E, et al. Comparing the 5-year diabetes outcomes of sleeve gastrectomy and gastric bypass: the National Patient-Centered Clinical Research Network (PCORNet) Bariatric Study. JAMA Surg. 2020;155(5):e200087. doi:10.1001/jamasurg.2020.0087 32129809
117 van Rijswijk AS, van Olst N, Schats W, van der Peet DL, van de Laar AW. What is weight loss after bariatric surgery expressed in percentage total weight loss (%TWL)? A systematic review. Obes Surg. 2021;31(8):3833-3847. doi:10.1007/s11695-021-05394-x 34002289
118 Buchwald H, Estok R, Fahrbach K, et al. Weight and type 2 diabetes after bariatric surgery: systematic review and meta-analysis. Am J Med. 2009;122(3):248-256 e5. doi:10.1016/j.amjmed.2008.09.041 19272486
119 Buse JB, Caprio S, Cefalu WT, et al. How do we define cure of diabetes? Diabetes Care. 2009;32(11):2133-2135. doi:10.2337/dc09-9036 19875608
120 Riddle MC, Cefalu WT, Evans PH, et al. Consensus Report: Definition and Interpretation of Remission in Type 2 Diabetes. Diabetes Care. 2021;44(10):2438-2444. doi:10.2337/dci21-0034 34462270
121 Carlsson LM, Peltonen M, Ahlin S, et al. Bariatric surgery and prevention of type 2 diabetes in Swedish obese subjects. N Engl J Med. 2012;367(8):695-704. doi:10.1056/NEJMoa1112082 22913680
122 Burke AE, Bennett WL, Jamshidi RM, et al. Reduced incidence of gestational diabetes with bariatric surgery. J Am Coll Surg. 2010;211(2):169-175. doi:10.1016/j.jamcollsurg.2010.03.029 20670854
123 Lee PC, Tan HC, Pasupathy S, et al. Effectiveness of bariatric surgery in diabetes prevention in high-risk Asian individuals. Singapore Med J. 2018;59(9):472-475. doi:10.11622/smedj.2018110 30310918
124 Xia Q, Campbell JA, Ahmad H, Si L, de Graaff B, Palmer AJ. Bariatric surgery is a cost-saving treatment for obesity. A comprehensive meta-analysis and updated systematic review of health economic evaluations of bariatric surgery. Obes Rev. 2020;21(1):e12932. doi:10.1111/obr.12932 31733033
125 McGlone ER, Carey I, Veličković V, et al. Bariatric surgery for patients with type 2 diabetes mellitus requiring insulin: clinical outcome and cost-effectiveness analyses. PLoS Med. 2020;17(12):e1003228. doi:10.1371/journal.pmed.1003228 33285553
126 Garfield SA, Malozowski S, Chin MH, et al. Considerations for diabetes translational research in real-world settings. Diabetes Care. 2003;26(9):2670-2674. doi:10.2337/diacare.26.9.2670 12941736
127 Yarnall KS, Pollak KI, Ostbye T, Krause KM, Michener JL. Primary care: is there enough time for prevention? Am J Public Health. 2003;93(4):635-641. doi:10.2105/ajph.93.4.635 12660210
128 Ali MK, McKeever Bullard K, Imperatore G, et al. Reach and use of diabetes prevention services in the United States, 2016–2017. JAMA Netw Open. 2019;2(5):e193160. doi:10.1001/jamanetworkopen.2019.3160 31074808
129 Ackermann RT. Working with the YMCA to implement the Diabetes Prevention Program. Am J Prev Med. 2013;44(Suppl 4):S352-S356. doi:10.1016/j.amepre.2012.12.010 23498298
130 Hernan WH, Brandle M, Zhang P, et al. Costs associated with the primary prevention of type 2 diabetes mellitus in the Diabetes Prevention Program. Diabetes Care. 2003;26(1):36-47. doi:10.2337/diacare.26.1.36 12502656
131 Lee AK, Warren B, Liu C, Foti K, Selvin E. Number and characteristics of US adults meeting prediabetes criteria for diabetes prevention programs: NHANES 2007–2016. J Gen Intern Med. 2019;34(8):1400-1402. doi:10.1007/s11606-019-04915-w 30859505
132 Vojta D, De Sa J, Prospect T, Stevens S. Effective interventions for stemming the growing crisis of diabetes and prediabetes: a national payer’s perspective. Health Aff (Millwood). 2012;31(1):20-26. doi:10.1377/hlthaff.2011.0327 22232090
133 U.S. Centers for Medicare & Medicaid Services (CMS). Medicare Diabetes Prevention Program (MDPP) Expanded Model. 2024. Updated September 10, 2024. Accessed October 29, 2024. https://www.cms.gov/priorities/innovation/innovation-models/medicare-diabetes-prevention-program
134 Ackermann RT, Finch EA, Brizendine E, Zhou H, Marrero DG. Translating the Diabetes Prevention Program into the community. The DEPLOY Pilot Study. Am J Prev Med. 2008;35(4):357-363. doi:10.1016/j.amepre.2008.06.035 18779029
135 Ackermann RT, Finch EA, Caffrey HM, Lipscomb ER, Hays LM, Saha C. Long-term effects of a community-based lifestyle intervention to prevent type 2 diabetes: the DEPLOY extension pilot study. Chronic Illn. 2011;7(4):279-290. doi:10.1177/1742395311407532 21840914
136 Ackermann RT, Liss DT, Finch EA, et al. A randomized comparative effectiveness trial for preventing type 2 diabetes. Am J Public Health. 2015;105(11):2328-2334. doi:10.2105/AJPH.2015.302641 26378828
137 Finch EA, Kelly MS, Marrero DG, Ackermann RT. Training YMCA wellness instructors to deliver an adapted version of the Diabetes Prevention Program lifestyle intervention. Diabetes Educ. 2009;35(2):224-228, 232. doi:10.1177/0145721709331420 19321808
138 Katula JA, Vitolins MZ, Morgan TM, et al. The Healthy Living Partnerships to Prevent Diabetes study: 2-year outcomes of a randomized controlled trial. Am J Prev Med. 2013;44(Suppl 4):S324-S332. doi:10.1016/j.amepre.2012.12.015 23498294
139 Ockene IS, Tellez TL, Rosal MC, et al. Outcomes of a Latino community-based intervention for the prevention of diabetes: the Lawrence Latino Diabetes Prevention Project. Am J Public Health. 2012;102(2):336-342. doi:10.2105/AJPH.2011.300357 22390448
140 O’Brien MJ, Squires AP, Bixby RA, Larson SC. Role development of community health workers: an examination of selection and training processes in the intervention literature. Am J Prev Med. 2009;37(6 Suppl 1):S262-S269. doi:10.1016/j.amepre.2009.08.011 19896028
141 Kramer MK, Vanderwood KK, Arena VC, et al. Evaluation of a Diabetes Prevention Program lifestyle intervention in older adults: a randomized controlled study in three senior/community centers of varying socioeconomic status. Diabetes Educ. 2018;44(2):118-129. doi:10.1177/0145721718759982 29514568
142 Ma J, Yank V, Xiao L, et al. Translating the Diabetes Prevention Program lifestyle intervention for weight loss into primary care: a randomized trial. JAMA Intern Med. 2013;173(2):113-121. doi:10.1001/2013.jamainternmed.987 23229846
143 Wilson MG, DeJoy DM, Vandenberg RJ, Corso P, Padilla H, Zuercher H. Effect of intensity and program delivery on the translation of Diabetes Prevention Program to worksites: a randomized controlled trial of Fuel Your Life. J Occup Environ Med. 2016;58(11):1113-1120. doi:10.1097/JOM.0000000000000873 27820761
144 Nicklas JM, Zera CA, England LJ, et al. A web-based lifestyle intervention for women with recent gestational diabetes mellitus: a randomized controlled trial. Obstet Gynecol. 2014;124(3):563-570. doi:10.1097/AOG.0000000000000420 25162257
145 U.S. Centers for Disease Control and Prevention (CDC). Prediabetes Risk Test. 2022. https://www.cdc.gov/prediabetes/risktest/index.html?CDC_AA_refVal=https%3A%2F%2Fwww.cdc.gov%2Fprediabetes%2Ftakethetest%2Findex.html
146 National Health Service (NHS) England. Surge in people checking their risk of type 2 diabetes. 2020. Accessed May 9, 2025. https://www.england.nhs.uk/2020/09/surge-in-people-checking-their-risk-of-type-2-diabetes/
147 Saaristo T, Peltonen M, Keinänen-Kiukaanniemi S, et al. National type 2 diabetes prevention programme in Finland: FIN-D2D. Int J Circumpolar Health. 2007;66(2):101-112. doi:10.3402/ijch.v66i2.18239 17515250
148 Patel MS, Small DS, Harrison JD, et al. Effectiveness of behaviorally designed gamification interventions with social incentives for increasing physical activity among overweight and obese adults across the United States: the STEP UP randomized clinical trial. JAMA Intern Med. 2019;179(12):1624-1632. doi:10.1001/jamainternmed.2019.3505 31498375
149 Ali MK, Echouffo-Tcheugui J, Williamson DF. How effective were lifestyle interventions in real-world settings that were modeled on the Diabetes Prevention Program? Health Aff (Millwood). 2012;31(1):67-75. doi:10.1377/hlthaff.2011.1009 22232096
150 Dunkley AJ, Bodicoat DH, Greaves CJ, et al. Diabetes prevention in the real world: effectiveness of pragmatic lifestyle interventions for the prevention of type 2 diabetes and of the impact of adherence to guideline recommendations: a systematic review and meta-analysis. Diabetes Care. 2014;37(4):922-933. doi:10.2337/dc13-2195 24652723
151 Mudaliar U, Zabetian A, Goodman M, et al. Cardiometabolic risk factor changes observed in diabetes prevention programs in US settings: a systematic review and meta-analysis. PLoS Med. 2016;13(7):e1002095. doi:10.1371/journal.pmed.1002095 27459705
152 Aziz Z, Absetz P, Oldroyd J, Pronk NP, Oldenburg B. A systematic review of real-world diabetes prevention programs: learnings from the last 15 years. Implement Sci. 2015;10:172. doi:10.1186/s13012-015-0354-6 26670418
153 Tabak RG, Sinclair KA, Baumann AA, et al. A review of Diabetes Prevention Program translations: use of cultural adaptation and implementation research. Transl Behav Med. 2015;5(4):401-414. doi:10.1007/s13142-015-0341-0 26622913
154 Herman WH, Hoerger TJ, Brandle M, et al. The cost-effectiveness of lifestyle modification or metformin in preventing type 2 diabetes in adults with impaired glucose tolerance. Ann Intern Med. 2005;142(5):323-332. doi:10.7326/0003-4819-142-5-200503010-00007 15738451
155 Ackermann RT, Marrero DG. Adapting the Diabetes Prevention Program lifestyle intervention for delivery in the community: the YMCA model. Diabetes Educ. 2007;33(1):69-78. doi:10.1177/0145721706297743 17272794
156 Vojta D, Koehler TB, Longjohn M, Lever JA, Caputo NF. A coordinated national model for diabetes prevention: linking health systems to an evidence-based community program. Am J Prev Med. 2013;44(4 Suppl 4):S301-S306. doi:10.1016/j.amepre.2012.12.018 23498291
157 Albright AL, Gregg EW. Preventing type 2 diabetes in communities across the U.S.: the National Diabetes Prevention Program. Am J Prev Med. 2013;44(4 Suppl 4):S346-S351. doi:10.1016/j.amepre.2012.12.009 23498297
158 U.S. Centers for Disease Control and Prevention (CDC). CDC Recognition Requirements for National Diabetes Prevention Program: Program Standards and Operating Procedures. U.S. Department of Health & Human Services. 2025. Accessed May 9, 2025. https://www.cdc.gov/diabetes-prevention/php/program-provider/program-requirements.html
159 Formagini T, Rodriguez D, Rezwan A, Naqvi JB, O’Brien MJ, Ng BP. Social vulnerability and National Diabetes Prevention Program recognition status. Am J Prev Med. 2025;68(1):172-175. doi:10.1016/j.amepre.2024.08.018 39218410
160 U.S. Centers for Medicare & Medicaid Services (CMS). Certification of Medicare Diabetes Prevention Program. Department of Health and Human Services. 2016. Accessed November 1, 2024. https://www.cms.gov/Research-statistics-Data-and-Systems/Research/ActuarialStudies/Downloads/Diabetes-Prevention-Certification-2016-03-14.pdf
161 Hoerger TJ, Jacobs S, Romaire M, et al. Evaluation of the Medicare Diabetes Prevention Program. 2022. https://www.cms.gov/priorities/innovation/data-and-reports/2022/mdpp-2ndannevalrpt
162 Institute for Clinical and Economic Review (ICER), Tice JA, Chapman R, et al. Diabetes Prevention Programs: Effectiveness and Value. Final Evidence Report and Meeting Summary. Institute for Clinical and Economic Review (ICER). 2016. Accessed May 15, 2025. https://icer.org/wp-content/uploads/2020/10/CTAF_DPP_Final_Evidence_Report_072516.pdf
163 LeFevre ML, U.S. Preventive Services Task Force. Behavioral counseling to promote a healthful diet and physical activity for cardiovascular disease prevention in adults with cardiovascular risk factors: U.S. Preventive Services Task Force Recommendation Statement. Ann Intern Med. 2014;161(8):587-593. doi:10.7326/M14-1796 25155419
164 U.S. Centers for Disease Control and Prevention (CDC). Diabetes Prevention Recognition Program Registry: Registry of All Recognized Programs. U.S. Department of Health and Human Services. 2024. Accessed June 5, 2025. https://dprp.cdc.gov/registry
165 Omada Health Inc. Omada For Prevention and Weight Health. 2024. Accessed May 12, 2025. https://www.omadahealth.com/prediabetes
166 Burd C, Gruss S, Albright A, Zina A, Schumacher P, Alley D. Translating knowledge into action to prevent type 2 diabetes: Medicare expansion of the National Diabetes Prevention Program lifestyle intervention. Milbank Q. 2020;98(1):172-196. doi:10.1111/1468-0009.12443 31994260
167 Laxy M, Zhang P, Ng BP, et al. Implementing lifestyle change interventions to prevent type 2 diabetes in US Medicaid programs: cost effectiveness, and cost, health, and health equity impact. Appl Health Econ Health Policy. 2020;18(5):713-726. doi:10.1007/s40258-020-00565-w 32607728
168 Desai JR, Vazquez-Benitez G, Taylor G, et al. The effects of financial incentives on Diabetes Prevention Program attendance and weight loss among low-income patients: the We Can Prevent Diabetes cluster-randomized controlled trial. BMC Public Health. 2020;20(1):1587. doi:10.1186/s12889-020-09683-5 33087083
169 National Association of Chronic Disease Directors (NACDD), Division of Diabetes Translation at the U.S. Centers for Disease Control and Prevention (CDC). Medicaid Coverage Landscape: Map and Visualizations. 2024. Accessed October 29, 2024. https://coveragetoolkit.org/medicaid-coverage-landscape/
170 U.S. Centers for Disease Control and Prevention (CDC). DPRP State Report. U.S. Department of Health & Human Services. 2024. Accessed June 5, 2025. https://nationaldppcsc.cdc.gov/s/article/DPRP-State-Report
171 Ely EK, Gruss SM, Luman ET, et al. A national effort to prevent type 2 diabetes: participant-level evaluation of CDC’s National Diabetes Prevention Program. Diabetes Care. 2017;40(10):1331-1341. doi:10.2337/dc16-2099 28500215
172 Cannon MJ, Ng BP, Lloyd K, Reynolds J, Ely EK. Delivering the National Diabetes Prevention Program: assessment of enrollment in in-person and virtual organizations. J Diabetes Res. 2022;2022:2942918. doi:10.1155/2022/2942918 35118160
173 Gruss SM, Nhim K, Gregg E, Bell M, Luman E, Albright A. Public health approaches to type 2 diabetes prevention: the US National Diabetes Prevention Program and beyond. Curr Diab Rep. 2019;19(9):78. doi:10.1007/s11892-019-1200-z 31385061
174 Joiner KL, Nam S, Whittemore R. Lifestyle interventions based on the Diabetes Prevention Program delivered via eHealth: a systematic review and meta-analysis. Prev Med. 2017;100:194-207. doi:10.1016/j.ypmed.2017.04.033 28456513
175 Bian RR, Piatt GA, Sen A, et al. The effect of technology-mediated diabetes prevention interventions on weight: a meta-analysis. J Med Internet Res. 2017;19(3):e76. doi:10.2196/jmir.4709 28347972
176 Ely EK, Ng BP, Cannon MJ. Delivering the National Diabetes Prevention Program: assessment of outcomes in in-person and virtual organizations. J Diabetes Res. 2023;2023:8894593. doi:10.1155/2023/8894593 37928892
177 Ng BP, Ely E, Papali’i M, Cannon MJ. Delivering the National Diabetes Prevention Program: assessment of retention, physical activity, and weight loss outcomes by participant characteristics and delivery modes. J Diabetes Res. 2024;2024:8461704. doi:10.1155/2024/8461704 39165352
178 Jayapaul-Philip B, Dai S, Kirtland K, Haslam A, Nhim K. Availability of the National Diabetes Prevention Program in United States counties, March 2017. Prev Chronic Dis. 2018;15:E109. doi:10.5888/pcd15.180063 30191810
179 Ariel-Donges AH, Gordon EL, Dixon BN, et al. Rural/urban disparities in access to the National Diabetes Prevention Program. Transl Behav Med. 2020;10(6):1554-1558. doi:10.1093/tbm/ibz098 31228199
180 Office of the Federal Register, National Archives and Records Administration. 42 CFR § 424.205 - Requirements for Medicare Diabetes Prevention Program Suppliers. 2024. https://www.ecfr.gov/current/title-42/chapter-IV/subchapter-B/part-424/subpart-I/section-424.205
181 U.S. Centers for Medicare & Medicaid Services (CMS). Medicare Diabetes Prevention Program: Quarterly Supplier Report. Department of Health and Human Services. 2025. Accessed July 19, 2025. https://data.cms.gov/cms-innovation-center-programs/disease-episode-based-payment-models/medicare-diabetes-prevention-program/data
182 Ritchie ND, Sauder KA, Gritz RM. Medicare Diabetes Prevention Program: where are the suppliers? Am J Manag Care. 2020;26(6):e198-e201. doi:10.37765/ajmc.2020.43496 32549070
183 Boltri JM, Tracer H, Strogatz D, et al. The National Clinical Care Commission Report to Congress: Leveraging Federal Policies and Programs to Prevent Diabetes in People With Prediabetes. Diabetes Care. 2023;46(2):e39-e50. doi:10.2337/dc22-0620 36701590
184 YMCA of the USA (YUSA). Diabetes Prevention Program FACT SHEET: December 2019. 2019. https://www.ymcaavery.com/wp-content/uploads/2021/02/YMCAs-Diabetes-Prevention-Program-Facts-2019.pdf
185 U.S. Centers for Disease Control and Prevention. National Diabetes Statistics Report: Prevalence of prediabetes among adults. U.S. Department of Health and Human Services. 2024. Updated May 15, 2024. Accessed October 29, 2024. https://www.cdc.gov/diabetes/php/data-research/index.html#cdc_report_pub_study_section_5-prevalence-of-prediabetes-among-adults.
186 O’Brien MJ, Perez A, Scanlan AB, et al. PREVENT-DM comparative effectiveness trial of lifestyle intervention and metformin. Am J Prev Med. 2017;52(6):788-797. doi:10.1016/j.amepre.2017.01.008 28237635
187 Cannon MJ, Masalovich S, Ng BP, et al. Retention among participants in the National Diabetes Prevention Program Lifestyle Change Program, 2012–2017. Diabetes Care. 2020;43(9):2042-2049. doi:10.2337/dc19-2366 32616617
188 Murray J, Craigs CL, Hill KM, Honey S, House A. A systematic review of patient reported factors associated with uptake and completion of cardiovascular lifestyle behaviour change. BMC Cardiovasc Disord. 2012;12:120. doi:10.1186/1471-2261-12-120 23216627
189 Hill-Briggs F, Adler NE, Berkowitz SA, et al. Social determinants of health and diabetes: a scientific review. Diabetes Care. 2020;44(1):258-279. doi:10.2337/dci20-0053 33139407
190 Kent-Marvick J, Knysheva M, Gibson B, Simonsen SE. Why do people choose to enroll or not enroll in the National Diabetes Prevention Program Lifestyle Change Program? A mixed-methods analysis from a sample of adults with a prediabetes diagnosis. J Prim Care Community Health. 2024;15. doi:10.1177/21501319241282862 39305089
191 Ritchie ND, Phimphasone-Brady P, Sauder KA, Amura CR. Perceived barriers and potential solutions to engagement in the National Diabetes Prevention Program. ADCES in Practice. 2021;9(1):16-20. doi:10.1177/2633559x20966275
192 Saju R, Castellon-Lopez Y, Turk N, et al. Differences in weight loss by race and ethnicity in the PRIDE trial: a qualitative analysis of participant perspectives. J Gen Intern Med. 2022;37(14):3715-3722. doi:10.1007/s11606-022-07521-5 35469358
193 Moin T, Li J, Duru OK, et al. Metformin prescription for insured adults with prediabetes from 2010 to 2012: a retrospective cohort study. Ann Intern Med. 2015;162(8):542-548. doi:10.7326/M14-1773 25894024
194 Tseng E, Yeh HC, Maruthur NM. Metformin use in prediabetes among U.S. adults, 2005–2012. Diabetes Care. 2017;40(7):887-893. doi:10.2337/dc16-1509 28373205
195 Hughes A, Khan T, Kirley K, et al. Metformin prescription rates for patients with prediabetes. J Am Board Fam Med. 2022;35(4):821-826. doi:10.3122/jabfm.2022.04.210485 35896449
196 Gulanski BI, Goulet JL, Radhakrishnan K, et al. Metformin prescription for U.S. veterans with prediabetes, 2010–2019. J Investig Med. 2024;72(1):139-150. doi:10.1177/10815589231201141 37668313
197 U.S. Preventive Services Task Force, Davidson KW, Barry MJ, et al. Screening for Prediabetes and Type 2 Diabetes: US Preventive Services Task Force Recommendation Statement. JAMA. 2021;326(8):736-743. doi:10.1001/jama.2021.12531 34427594
198 Glasgow RE, Harden SM, Gaglio B, et al. RE-AIM planning and evaluation framework: adapting to new science and practice with a 20-year review. Front Public Health. 2019;7:64. doi:10.3389/fpubh.2019.00064 30984733
199 Ali MK, Imperatore G, Benoit SR, et al. Impact of changes in diabetes screening guidelines on testing eligibility and potential yield among adults without diagnosed diabetes in the United States. Diabetes Res Clin Pract. 2023;197:110572. doi:10.1016/j.diabres.2023.110572 36775024
200 Casagrande SS, Cowie CC, Genuth SM. Self-reported prevalence of diabetes screening in the U.S., 2005–2010. Am J Prev Med. 2014;47(6):780-787. doi:10.1016/j.amepre.2014.07.039 25241199
201 O’Brien MJ, Zhang Y, Bailey SC, et al. Screening for prediabetes and diabetes: clinical performance and implications for health equity. Am J Prev Med. 2023;64(6):814-823. doi:10.1016/j.amepre.2023.01.007 37171231
202 Obinwa U, Perez A, Lingvay I, Meneghini L, Halm EA, Bowen ME. Multilevel variation in diabetes screening within an integrated health system. Diabetes Care. 2020;43(5):1016-1024. doi:10.2337/dc19-1622 32139383
203 Banerjee ES, Shaak K, Burgess N, Johnson M, Careyva B. Factors associated with clinician adherence to USPSTF diabetes screening recommendations. J Prim Care Community Health. 2021;12. doi:10.1177/21501327211016579 34151635
204 Evron JM, Herman WH, McEwen LN. Changes in screening practices for prediabetes and diabetes since the recommendation for hemoglobin A(1c) testing. Diabetes Care. 2019;42(4):576-584. doi:10.2337/dc17-1726 30728220
205 Yang K, Lee YS, Chasens ER. Outcomes of health care providers’ recommendations for healthy lifestyle among U.S. adults with prediabetes. Metab Syndr Relat Disord. 2011;9(3):231-237. doi:10.1089/met.2010.0112 21361822
206 Dorsey R, Songer T. Lifestyle behaviors and physician advice for change among overweight and obese adults with prediabetes and diabetes in the United States, 2006. Prev Chronic Dis. 2011;8(6):A132. https://www.cdc.gov/pcd/issues/2011/nov/10_0221.htm 22005625
207 Geiss LS, James C, Gregg EW, Albright A, Williamson DF, Cowie CC. Diabetes risk reduction behaviors among U.S. adults with prediabetes. Am J Prev Med. 2010;38(4):403-409. doi:10.1016/j.amepre.2009.12.029 20307809
208 Ad Council. Type 2 Diabetes Prevention Campaign Site. Centers for Disease Control and Prevention. 2024. Accessed May 5, 2025. https://www.adcouncil.org/campaign/type-2-diabetes-prevention
209 American Medical Association (AMA). AMA Prediabetes Quality Measures. 2024. Accessed January 14, 2025. https://www.ama-assn.org/delivering-care/prevention-wellness/ama-prediabetes-quality-measures
210 Li Y, Geiss L, Burrows N, Rolka D, Albright A. Awareness of prediabetes—United States, 2005–2010. MMWR Morb Mortal Wkly Rep. 2013;62(11):209-212. https://www.cdc.gov/mmwr/preview/mmwrhtml/mm6211a4.htm 23515058
211 Formagini T, Brooks JV, Roberts A, et al. Prediabetes prevalence and awareness by race, ethnicity, and educational attainment among U.S. adults. Front Public Health. 2023;11:1277657. doi:10.3389/fpubh.2023.1277657 38164446
212 Scanlan AB, Maia CM, Perez A, Homko CJ, O’Brien MJ. Diabetes risk assessment in Latinas: effectiveness of a brief diabetes risk questionnaire for detecting prediabetes in a community-based sample. Diabetes Spectr. 2018;31(1):31-36. doi:10.2337/ds16-0051 29456424
213 Smith JD, Li DH, Merle JL, Keiser B, Mustanski B, Benbow ND. Adjunctive interventions: change methods directed at recipients that support uptake and use of health innovations. Implement Sci. 2024;19(1):10. doi:10.1186/s13012-024-01345-z 38331832
214 U.S. Centers for Disease Control and Prevention, National Diabetes Prevention Program. Personal Success Tool. 2024. Accessed October 30, 2024. https://www.cdc.gov/diabetes-prevention/php/lifestyle-change-resources/personal-success-tool-pst.html
215 U.S. Centers for Disease Control and Prevention (CDC), National Diabetes Prevention Program. Discovery Session Guide for In Person Delivery. U.S. Department of Health and Human Services. 2023. Accessed April 5, 2025. https://nationaldppcsc.cdc.gov/s/article/in-person-discovery-session-guide
216 Pinelli NR, Herman WH, Brown MB, Jaber LA. Perceived risk and the willingness to enroll in a diabetes prevention lifestyle intervention in Arab-Americans. Diabetes Res Clin Pract. 2010;90(2):e27-e29. doi:10.1016/j.diabres.2010.08.010 20833442
217 Ritchie ND, Kaufmann PG, Gritz RM, Sauder KA, Holtrop JS. Presessions to the National Diabetes Prevention Program may be a promising strategy to improve attendance and weight loss outcomes. Am J Health Promot. 2019;33(2):289-292. doi:10.1177/0890117118786195 29986597
218 Williams PA, Rotunda W, Porterfield D, Skeete RA, Smith AD, Proia KK. Implementation of Session Zero as a recruitment strategy in the National Diabetes Prevention Program’s Lifestyle Change Program. Sci Diabetes Self Manag Care. 2024;50(1):74-86. doi:10.1177/26350106231215767 38158815
219 Adams R, Hebert CJ, McVey L, Williams R. Implementation of the YMCA Diabetes Prevention Program throughout an integrated health system: a translational study. Perm J. 2016;20(4):15-241. doi:10.7812/TPP/15-241 27828773
220 Brunisholz KD, Joy EA, Hamilton S, Greenwood MR. From clinic to community: a framework for providing diabetes prevention services that cross the care continuum. Qual Manag Health Care. 2017;26(4):218-220. doi:10.1097/QMH.0000000000000147 28991818
221 Moin T, Duru OK, Turk N, et al. Effectiveness of shared decision-making for diabetes prevention: 12-month results from the Prediabetes Informed Decision and Education (PRIDE) Trial. J Gen Intern Med. 2019;34(11):2652-2659. doi:10.1007/s11606-019-05238-6 31471729
222 Bandi K, Vargas MC, Lopez A, et al. Development and evaluation of a prediabetes decision aid in primary care: examining patient-reported outcomes by language preference and educational attainment. Sci Diabetes Self Manag Care. 2021;47(3):216-227. doi:10.1177/26350106211009189 34000911
223 O’Brien MJ, Cameron KA, Vargas MC, et al. Evaluation of a prediabetes decision aid on patient-reported outcomes in primary care: a pilot study. J Gen Intern Med. 2021;36(3):824-826. doi:10.1007/s11606-020-05936-6 32542497
224 Nguyen V, Ara P, Simmons D, Osuagwu UL. The role of digital health technology interventions in the prevention of type 2 diabetes mellitus: a systematic review. Clin Med Insights Endocrinol Diabetes. 2024;17. doi:10.1177/11795514241246419 38779330
225 Pew Research Center. Mobile Fact Sheet: Tech Adoption Trends. 2024. Accessed April 5, 2025. https://www.pewresearch.org/internet/fact-sheet/mobile/
226 World Economic Forum. Charted: There are more mobile phones than people in the world. 2023. Accessed November 4, 2024. https://www.weforum.org/stories/2023/04/charted-there-are-more-phones-than-people-in-the-world/#:~:text=According%20to%20the%20International%20Telecommunication,Image%3A%20Statista
227 Katula JA, Dressler EV, Kittel CA, et al. Effects of a digital Diabetes Prevention Program: an RCT. Am J Prev Med. 2022;62(4):567-577. doi:10.1016/j.amepre.2021.10.023 35151522
228 Arora S, Lam CN, Burner E, Menchine M. Implementation and evaluation of an automated text message-based diabetes prevention program for adults with pre-diabetes. J Diabetes Sci Technol. 2024;18(5):1139-1145. doi:10.1177/19322968231162601 36946537
229 Grock S, Ku JH, Kim J, Moin T. A review of technology-assisted interventions for diabetes prevention. Curr Diab Rep. 2017;17(11):107. doi:10.1007/s11892-017-0948-2 28942537
230 Chin SO, Keum C, Woo J, et al. Successful weight reduction and maintenance by using a smartphone application in those with overweight and obesity. Sci Rep. 2016;6(1):34563. doi:10.1038/srep34563 27819345
231 Ebekozien O, Fantasia K, Farrokhi F, Sabharwal A, Kerr D. Technology and health inequities in diabetes care: How do we widen access to underserved populations and utilize technology to improve outcomes for all? Diabetes Obes Metab. 2024;26(Suppl 1):3-13. doi:10.1111/dom.15470 38291977
232 Ng BP, Hawkins GT, Massey M, LaManna JB, Park C. Digital divide among Medicare beneficiaries and the Diabetes Prevention Program. Am J Prev Med. 2024;67(5):746-752. doi:10.1016/j.amepre.2024.06.019 38909662
233 Goldstein SP, Tovar A, Espel-Huynh HM, Stowers KC. Applying a social determinants of health framework to guide digital innovations that reduce disparities in chronic disease. Psychosom Med. 2023;85(7):659-669. doi:10.1097/PSY.0000000000001176 36800264
234 Wadi NM, Asantewa-Ampaduh S, Rivas C, Goff LM. Culturally tailored lifestyle interventions for the prevention and management of type 2 diabetes in adults of Black African ancestry: a systematic review of tailoring methods and their effectiveness. Public Health Nutr. 2022;25(2):422-436. doi:10.1017/S1368980021003682 34435943
235 McCurley JL, Gutierrez AP, Gallo LC. Diabetes prevention in U.S. Hispanic adults: a systematic review of culturally tailored interventions. Am J Prev Med. 2017;52(4):519-529. doi:10.1016/j.amepre.2016.10.028 27989451
236 Hall DL, Lattie EG, McCalla JR, Saab PG. Translation of the Diabetes Prevention Program to ethnic communities in the United States. J Immigr Minor Health. 2016;18(2):479-489. doi:10.1007/s10903-015-0209-x 25910619
237 Lucero JE, Roubideaux Y. Advancing diabetes prevention and control in American Indians and Alaska Natives. Annu Rev Public Health. 2022;43:461-475. doi:10.1146/annurev-publhealth-093019-010011 35380066
238 Weber MB, Hennink MM, Narayan KMV. Tailoring lifestyle programmes for diabetes prevention for US South Asians. Fam Med Community Health. 2020;8(2):e000295. doi:10.1136/fmch-2019-000295 32341773
239 Whitaker M, Aguirre MC, Gutierrez Chavez M, et al. Couple-based lifestyle intervention to prevent type 2 diabetes: protocol for a randomised pilot trial. BMJ Open. 2023;13(2):e068623. doi:10.1136/bmjopen-2022-068623 36797025
240 Chambers EC, Gonzalez JS. Power-Up: An Effectiveness Trial of the Diabetes Prevention Program Tailored for Black and Latino Men. NIH RePORTER. 2019. Accessed November 5, 2024. https://reporter.nih.gov/project-details/10908006
241 Gorczyca AM. The National Diabetes Prevention Program in Rural Communities. NIH RePORTER. 2023. Accessed November 5, 2024. https://reporter.nih.gov/search/u8iFdIVblU2ALY2x7T39bQ/project-details/10929467
242 Beasley JM, Chodosh J. BRinging the Diabetes Prevention Program to GEriatric Populations (BRIDGE). NIH RePORTER. 2021. Accessed November 5, 2024. https://reporter.nih.gov/search/u8iFdIVblU2ALY2x7T39bQ/project-details/10746123
243 Magge SN. The PRIORITY Study: from PRedIctiOn to pReventIon of youth-onset TYpe 2 diabetes. NIH RePORTER. 2023. Accessed November 5, 2024. https://reporter.nih.gov/search/u8iFdIVblU2ALY2x7T39bQ/project-details/10792872
244 Duru OK, Moin T. A Shared Decision Making Intervention for Diabetes Prevention in Women with a History of Gestational Diabetes Mellitus. NIH RePORTER. 2021. Accessed November 5, 2024. https://reporter.nih.gov/search/u8iFdIVblU2ALY2x7T39bQ/project-details/10766701
245 Venkataramani M. Family-Oriented Diabetes Prevention: Augmenting the Diabetes Prevention Program. NIH RePORTER. 2019. Accessed November 5, 2024. https://reporter.nih.gov/search/u8iFdIVblU2ALY2x7T39bQ/project-details/10621957
246 Anoke SC, Normand SL, Zigler CM. Approaches to treatment effect heterogeneity in the presence of confounding. Stat Med. 2019;38(15):2797-2815. doi:10.1002/sim.8143 30931547
247 Kent DM, Hayward RA. Limitations of applying summary results of clinical trials to individual patients: the need for risk stratification. JAMA. 2007;298(10):1209-1212. doi:10.1001/jama.298.10.1209 17848656
248 Diabetes Prevention Program (DPP) Research Group. Long-term effects of metformin on diabetes prevention: identification of subgroups that benefited most in the Diabetes Prevention Program and Diabetes Prevention Program Outcomes Study. Diabetes Care. 2019;42(4):601-608. doi:10.2337/dc18-1970 30877090
249 Sussman JB, Kent DM, Nelson JP, Hayward RA. Improving diabetes prevention with benefit based tailored treatment: risk based reanalysis of Diabetes Prevention Program. BMJ. 2015;350:h454. doi:10.1136/bmj.h454 25697494
250 Herman WH, Pan Q, Edelstein SL, et al. Impact of lifestyle and metformin interventions on the risk of progression to diabetes and regression to normal glucose regulation in overweight or obese people with impaired glucose regulation. Diabetes Care. 2017;40(12):1668-1677. doi:10.2337/dc17-1116 29021207
251 Raghavan S, Jablonski K, Delahanty LM, et al. Interaction of diabetes genetic risk and successful lifestyle modification in the Diabetes Prevention Programme. Diabetes Obes Metab. 2021;23(4):1030-1040. doi:10.1111/dom.14309 33394545
252 Billings LK, Jablonski KA, Pan Q, et al. Increased genetic risk for beta-cell failure is associated with beta-cell function decline in people with prediabetes. Diabetes. 2024;73(8):1352-1360. doi:10.2337/db23-0761 38758294
253 Valabhji J, Barron E, Bradley D, et al. Early outcomes from the English National Health Service Diabetes Prevention Programme. Diabetes Care. 2020;43(1):152-160. doi:10.2337/dc19-1425 31719054
254 Zhang X, Gregg EW, Williamson DF, et al. A1C level and future risk of diabetes: a systematic review. Diabetes Care. 2010;33(7):1665-1673. doi:10.2337/dc09-1939 20587727
255 Perreault L, Pan Q, Schroeder EB, et al. Regression from prediabetes to normal glucose regulation and prevalence of microvascular disease in the Diabetes Prevention Program Outcomes Study (DPPOS). Diabetes Care. 2019;42(9):1809-1815. doi:10.2337/dc19-0244 31320445
256 Selvin E, Coresh J, Golden SH, Brancati FL, Folsom AR, Steffes MW. Glycemic control and coronary heart disease risk in persons with and without diabetes: the Atherosclerosis Risk in Communities Study. Arch Intern Med. 2005;165(16):1910-1916. doi:10.1001/archinte.165.16.1910 16157837
257 Selvin E, Steffes MW, Zhu H, et al. Glycated hemoglobin, diabetes, and cardiovascular risk in nondiabetic adults. N Engl J Med. 2010;362(9):800-811. doi:10.1056/NEJMoa0908359 20200384
258 Butalia S, Chu LM, Dover DC, et al. Association between hemoglobin A1c and development of cardiovascular disease in Canadian men and women without diabetes at baseline: a population-based study of 608 474 adults. J Am Heart Assoc. 2024;13(9):e031095. doi:10.1161/JAHA.123.031095 38639364
259 Morris DH, Khunti K, Achana F, et al. Progression rates from HbA1c 6.0–6.4% and other prediabetes definitions to type 2 diabetes: a meta-analysis. Diabetologia. 2013;56(7):1489-1493. doi:10.1007/s00125-013-2902-4 23584433
260 Koyama AK, Bullard KM, Pavkov ME, Park J, Mardon R, Zhang P. Progression to diabetes among older adults with hemoglobin A1c-defined prediabetes in the US. JAMA Netw Open. 2022;5(4):e228158. doi:10.1001/jamanetworkopen.2022.8158 35442457
261 Lindström J, Ilanne-Parikka P, Peltonen M, et al. Sustained reduction in the incidence of type 2 diabetes by lifestyle intervention: follow-up of the Finnish Diabetes Prevention Study. Lancet. 2006;368(9548):1673-1679. doi:10.1016/S0140-6736(06)69701-8 17098085
262 Kosaka K, Noda M, Kuzuya T. Prevention of type 2 diabetes by lifestyle intervention: a Japanese trial in IGT males. Diabetes Res Clin Pract. 2005;67(2):152-162. doi:10.1016/j.diabres.2004.06.010 15649575
263 Saito T, Watanabe M, Nishida J, et al. Lifestyle modification and prevention of type 2 diabetes in overweight Japanese with impaired fasting glucose levels: a randomized controlled trial. Arch Intern Med. 2011;171(15):1352-1360. doi:10.1001/archinternmed.2011.275 21824948
264 Iqbal Hydrie MZ, Basit A, Shera AS, Hussain A. Effect of intervention in subjects with high risk of diabetes mellitus in Pakistan. J Nutr Metab. 2012;2012:867604. doi:10.1155/2012/867604 22888411
265 Weber MB, Ranjani H, Staimez LR, et al. The stepwise approach to diabetes prevention: results from the D-CLIP randomized controlled trial. Diabetes Care. 2016;39(10):1760-1767. doi:10.2337/dc16-1241 27504014
266 Jarrett RJ, Keen H, Fuller JH, McCartney M. Worsening to diabetes in men with impaired glucose tolerance (“borderline diabetes”). Diabetologia. 1979;16(1):25-30. doi:10.1007/BF00423146 761734
267 Li CL, Pan CY, Lu JM, et al. Effect of metformin on patients with impaired glucose tolerance. Diabet Med. 1999;16(6):477-481. doi:10.1046/j.1464-5491.1999.00090.x 10391395
268 Buchanan TA, Xiang AH, Peters RK, et al. Preservation of pancreatic beta-cell function and prevention of type 2 diabetes by pharmacological treatment of insulin resistance in high-risk Hispanic women. Diabetes. 2002;51(9):2796-2803. doi:10.2337/diabetes.51.9.2796 12196473
269 Buchanan TA, Xiang AH, Peters RK, et al. Protection from type 2 diabetes persists in the TRIPOD cohort eight months after stopping troglitazone. Diabetes. 2001;50(Suppl 2):A81.
270 DREAM Trial Investigators, Bosch J, Yusuf S, et al. Effect of ramipril on the incidence of diabetes. N Engl J Med. 2006;355(15):1551-1562. doi:10.1056/NEJMoa065061 16980380
271 DREAM Trial Investigators, Gerstein HC, Yusuf S, et al. Effect of rosiglitazone on the frequency of diabetes in patients with impaired glucose tolerance or impaired fasting glucose: a randomised controlled trial. Lancet. 2006;368(9541):1096-1105. doi:10.1016/S0140-6736(06)69420-8 16997664
272 DeFronzo RA, Tripathy D, Schwenke DC, et al. Pioglitazone for diabetes prevention in impaired glucose tolerance. N Engl J Med. 2011;364(12):1104-1115. doi:10.1056/NEJMoa1010949 21428766
273 Tripathy D, Schwenke DC, Banerji M, et al. Diabetes incidence and glucose tolerance after termination of pioglitazone therapy: results from ACT NOW. J Clin Endocrinol Metab. 2016;101(5):2056-2062. doi:10.1210/jc.2015-4202 26982008
274 NAVIGATOR Study Group, Holman RR, Haffner SM, et al. Effect of nateglinide on the incidence of diabetes and cardiovascular events. N Engl J Med. 2010;362(16):1463-1476. doi:10.1056/NEJMoa1001122 20228402
275 NAVIGATOR Study Group, McMurray JJ, Holman RR, et al. Effect of valsartan on the incidence of diabetes and cardiovascular events. N Engl J Med. 2010;362(16):1477-1490. doi:10.1056/NEJMoa1001121 20228403
276 Kawamori R, Tajima N, Iwamoto Y, et al. Voglibose for prevention of type 2 diabetes mellitus: a randomised, double-blind trial in Japanese individuals with impaired glucose tolerance. Lancet. 2009;373(9675):1607-1614. doi:10.1016/S0140-6736(09)60222-1 19395079
277 Holman RR, Coleman RL, Chan JCN, et al. Effects of acarbose on cardiovascular and diabetes outcomes in patients with coronary heart disease and impaired glucose tolerance (ACE): a randomised, double-blind, placebo-controlled trial. Lancet Diabetes Endocrinol. 2017;5(11):877-886. doi:10.1016/S2213-8587(17)30309-1 28917545
278 U.S. Bureau of Labor Statistics (BLS). Consumer Price Index for All Urban Consumers; Medical Care in U.S. City Average (CUUR0000SAM). U.S. Bureau of Labor Statistics, Division of Consumer Price and Price Indexes. 2025. Accessed July 5, 2025. https://www.bls.gov/cpi/data.htm
279 Grenda TR, Pradarelli JC, Thumma JR, Dimick JB. Variation in hospital episode costs with bariatric surgery. JAMA Surg. 2015;150(12):1109-1115. doi:10.1001/jamasurg.2015.2394 26376433

FIGURE 1.

Relationships Between A1C Level and the 10-Year Cumulative Incidence of Type 2 Diabetes and Its Complications: Implications for How the Goals for Prevention Differ From Treatment.

Figure 1 depicts the proportion of individuals with incident future events based on their level of A1C. The 10-year risks for long-term microvascular and macrovascular complications are plotted for all levels of A1C; the 10-year risk for incident type 2 diabetes is plotted only for groups with A1C below the type 2 diabetes diagnosis threshold of <6.5%. Risk of type 2 diabetes by A1C is adapted from Zhang et al. (2010) (254). Risks for retinopathy and nephropathy by A1C are adapted from Perreault et al. (2019) (255). Risk for CHD events by A1C is adapted from hazard ratios reported from the Atherosclerosis Risk in Communities Study by Selvin et al. (2005) (256) and Selvin et al. (2010) (257) and applied to published population-based estimates of incident CHD by A1C (258). A conversion formula for A1C values is available in the Conversions section. A1C, glycated hemoglobin; CHD, coronary heart disease.

SOURCE: References are listed within the footer.

Line graph showing that primary prevention interventions can prevent or delay the need for type 2 diabetes treatments and can improve long term quality of life and life expectancy.

FIGURE 2.

Trends in Prediabetes Prevalence and Awareness in Adults, U.S., 2005–2029.

Data beyond 2020 are estimated based on a linear forecast trend derived from historical data.

SOURCE: Reference (3)

Bar graph showing that while prediabetes awareness remains low there was a slight increase in awareness between 2005 and 2020 from 7 to 17 percent.

TABLE 1.

Prediabetes Phenotypes and Their Corresponding Pathophysiologic Defects

CHARACTERISTIC OR DEFECT | IMPAIRED FASTING GLUCOSE (IFG) | IMPAIRED GLUCOSE TOLERANCE (IGT) | BOTH IFG AND IGT | ELEVATED A1C
Glycemic definition | Plasma glucose after an 8–14 hour fast: 100–125 mg/dL | Plasma glucose 2-hours after ingesting 75 g oral glucose: 140–199 mg/dL | Fasting glucose: 100–125 mg/dL AND 2-hour plasma glucose: 140–199 mg/dL | A1C: 5.7%–6.4%
Glucose abnormality | ↑ fasting blood glucose | ↑ post-prandial blood glucose | ↑ fasting and post-prandial blood glucose | ↑ average blood glucose over the past 40–70 days*
Insulin resistance | Liver | Muscle | Combination | Variable
ß-cell defect | ↓ first-phase insulin secretion (43) | ↓ first- and late-phase insulin secretion (43) | ↓ first- and late-phase insulin secretion (43) | Variable ↓ first- and late-phase insulin secretion, even if IFG & IGT absent (44)
Annual risk of progression | 3.6%^†^ | 4.6%^†^ | 7.0%^†^ | 2.8%–5.4%^‡^

Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; IFG, impaired fasting glucose; IGT, impaired glucose tolerance; RBC, red blood cell.

* The presence of IFG and IGT may both contribute to average blood glucose and A1C levels. However, only 37% of adults with A1C 5.7%–6.4% have IFG and only 31% have IGT; 61% of adults with prediabetes overall have A1C values <5.7% (47). The mean lifespan of RBCs is 110–120 days, but at any point in time, the mean current age of RBCs in a blood specimen is 40–70 days (45,46).

† Estimates on progression from IFG and IGT to type 2 diabetes are derived from the meta-analysis by Morris et al. (259).

‡ Morris et al. only report incident diabetes events for adults with A1C 6.0%–6.4%, so estimates for annualized rates of progression from A1C 5.7%–6.4% to type 2 diabetes are derived from studies by Koyama et al. (260) (2.8%), Zhang et al. (254) (5.4%), and Selvin et al. (257) (3.4%).

SOURCE: References are listed within the table and footer.

TABLE 2.

Randomized Trials With Primary Prevention of Type 2 Diabetes as a Principal Outcome

STUDY, LOCATION, REPORT YEAR (REF.) | INTERVENTION | ELIGIBILITY | N OF SUBJECTS RANDOMIZED | EFFECT SIZE (95% CI)* | EFFECTS OF REMOVING TREATMENT^†^
Lifestyle Behavioral Interventions^‡^
Da Qing Study, China, 1997 (49) | Intensive Lifestyle Recurring (weekly tapering to quarterly) dietary and/or physical activity counseling with a weight loss goal of 0.5–1 kg per month, if BMI ≥25 kg/m^2^ | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL | 577 (cluster randomized by 33 clinics; outcome analysis included 530 subjects) | T2D incidence (trial period: 6.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 6-yr I (%)]...[underlined: RR (95% CI)*] Placebo.................15.7..............67.7...............Ref......... Diet........................10.0.............43.8.......0.71 (0.57–0.88) Exercise..................8.3..............41.1.......0.61 (0.49–0.77) Both........................9.6..............46.0.......0.69 (0.55–0.86) | During 14 years of follow-up after stopping lifestyle interventions, cumulative incidence of T2D gradually approached but never reached the rate for placebo subjects (52).
Diabetes Prevention Study (DPS), Finland, 2001 (50) | Intensive Lifestyle Recurring (roughly monthly) dietary and physical activity counseling with a weight loss goal of ≥5% | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥25 kg/m^2^ | 522 | T2D incidence (mean trial period: 3.2 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 4-yr CIR (%)]...[underlined: HR(95% CI)*] Placebo..................7.8..................23..................Ref........... Lifestyle.................3.2..................11..............0.4 (0.3–0.7) ★Mean weight loss with lifestyle intervention was 3.4 kg greater at 1 year and 2.7 kg greater at 2 years than placebo. | During 3 years of follow-up after stopping intensive lifestyle interventions, 20.5% of placebo and 14.0% of lifestyle subjects who remained at risk had T2D confirmed; HR 0.61 (95% CI 0.38–0.98) (261).
Diabetes Prevention Program (DPP), U.S., 2002 (51) | Intensive Lifestyle Recurring (weekly to monthly) dietary, physical activity, and behavioral skills counseling with a weight loss goal of ≥7% | FPG 95–125 mg/dL AND IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥24 kg/m^2^ (≥22 kg/m^2^ if Asian) | 3,234 | T2D incidence (mean trial period: 2.8 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo................11.0.................28.9..................Ref........... Lifestyle................4.8.................14.4...........0.42 (0.34–0.52) ★Mean weight loss for lifestyle subjects was 5.5 kg greater than placebo at 2.8 years. | During 5.7 years of follow-up after beginning to offer intensive lifestyle support to [underlined: both] placebo and lifestyle subjects, T2D incidence for placebo subjects dropped to 5.6 per 100 PY, which was NS from lifestyle subjects (82).
Kosaka, Japan, 2005 (262) | Moderate Lifestyle Recurring (every 2–3 months) dietary and/or physical activity counseling with a weight loss goal of 0.5–1 kg per month if BMI ≥25 kg/m^2^ | 100 g, 2-hr plasma glucose 160–239 mg/dL FPG <140 mg/dL Men only | 484 (outcome analysis included 458 subjects) | T2D incidence (mean trial period: 3.9 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 4-yr CIR (%)]...[underlined: IRR (95% CI)*] Placebo.................NR...................9.3...................Ref........... Lifestyle................NR...................3.0............0.32 (0.06–1.01) ★At year 4, the lifestyle group had lost 1.8 kg more than the placebo group (p<0.001). | NR
Indian Diabetes Prevention Programme-1, India, 2006 (83) | Moderate Lifestyle Recurring (twice annual plus monthly telephone call) dietary and physical activity counseling; monthly phone calls; no specified weight loss goal. With and without metformin 250 mg twice daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL 79% men | 531 (outcome analysis included 502 subjects) | T2D incidence (mean trial period: 2.5 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: IRR (95% CI)*] Placebo................NR....................55.0...................Ref......... Lifestyle...............NR....................39.3..........0.72 (0.63–0.80) Lifestyle + Metformin............NR....................39.5..........0.72 (0.63–0.80) ★At year 3, mean weight changes for all intervention and control groups were similar. | NR
Zensharen Trial, Japan, 2011 (263) | Moderate Lifestyle Recurring (four visits in 6 months tapering to twice annual) dietary and physical activity counseling with a weight loss goal of ≥5% | FPG 100–125 mg/dL No diabetes by baseline OGTT (41% IGT) BMI ≥24 kg/m^2^ Age 30–60 yrs | 641 | T2D incidence (mean trial period: 2.6 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo............5.8.....................16.6...................Ref........... Lifestyle...........4.2.....................12.2............0.56 (0.36–0.87) ★HR 0.41 (95% CI 0.24–0.69) in subset with IFG+IGT ★HR 0.24 (95% CI 0.12–0.48) in subset with IFG+A1C ≥6.0% ★Mean weight loss was 1.4 kg greater after 12 months for lifestyle compared with placebo group. | NR
Karachi Prevention Trial, Pakistan, 2012 (264) | Moderate Lifestyle Recurring (every 2 months) dietary and physical activity counseling with a weight loss goal of ≥5%. With and without metformin 500 mg twice daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL Age ≥30 yrs | 317 (outcome analysis included 274 subjects) | T2D incidence (trial period: 1.5 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 1.5-yr CIR (%)]...[underlined: RR (95% CI)*] Placebo...........10.3......................NR.......................Ref......... Lifestyle............3.0......................NR..............0.29 (0.10–0.86) Lifestyle + Metformin.........2.8......................NR..............0.24 (0.07–0.80) | NR
D-CLIP “Step Therapy” Trial, India, 2016 (265) | Intensive, Short-term Lifestyle 4–6 months of weekly to monthly dietary, physical activity, and behavioral skills counseling with a weight loss goal of ≥7% PLUS Metformin 500 mg twice daily added at any time after month 4, if individual had combined IFG+IGT or IFG+A1C 5.7%–6.4% | FPG 100–125 mg/dL OR IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥23 kg/m^2^ OR waist circumference ≥90 cm for men or ≥80 cm for women | 578 (outcome analysis included 550 subjects) | T2D incidence (trial period: 3.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: RR (95% CI)*] Placebo..................14.2................34.9................Ref........... Lifestyle ± Metformin................9.8................25.7.........0.68 (0.50–0.93) ★155 (55%) of those randomized to lifestyle added metformin therapy during the trial. ★Mean weight loss was 2.1 kg greater at 6 months (end of lifestyle intervention) for lifestyle compared with placebo group; at 3 years, the lifestyle arm regained 93% of their weight loss but weight was still 0.7 kg lower in the lifestyle group compared to placebo. | NR
Biguanide Medication Interventions
Whitehall, U.K., 1979 (266) | Phenformin 50 mg daily PLUS: [underlined: Brief] dietary counseling to restrict daily table sugar consumption OR (two arms) [underlined: Brief] dietary counseling to restrict carbohydrates to 120 g daily | 50 g, 2-hr plasma glucose 120–199 mg/dL Men only | 204 (outcome assessed for 181 subjects) | T2D incidence (trial period: 5 yrs) ....................[underlined: Rate (/100 PY)].....[underlined: 5-yr I (%)].....[underlined: RR (95% CI)*] Placebo..................NR.................15.7.................Ref........... Phenformin.............NR................14.1.........0.90 (0.45–1.80) ★Factorial randomization to two brief dietary interventions showed no interaction effects. | NR
Chinese Shougang Corporation Trial, 1999 (267) | Metformin 250 mg three times daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL | 90 (outcome analysis included 85) | T2D incidence (trial period: 1 yr) ....................[underlined: Rate (/100 PY)]...[underlined: 1-yr I (%)]...[underlined: RR (95% CI)*] Placebo..................NR................14.0..............Ref.......... Metformin..............NR.................7.1.......0.51 (0.14–1.91) | NR
DPP, U.S., 2002 (51) | Metformin 850 mg twice daily | FPG 95–125 mg/dL AND IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥24 kg/m^2^ (≥22 kg/m^2^ if Asian) | 3,234 | T2D incidence (mean trial period: 2.8 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo.................11.0................28.9.................Ref........... Metformin..............7.8................21.7..........0.69 (0.57–0.83) ★Mean weight loss for metformin subjects was 2.0 kg greater than placebo subjects at 2.8 years. | When retesting 1–2 weeks after stopping metformin, 7.2% of metformin and 5.0% of placebo subjects who remained at risk had T2D confirmed; difference NS: OR 1.49 (95% CI 0.93–2.38) (109).
Indian Diabetes Prevention Programme-1, India, 2006 (83) | Metformin 250 mg twice daily With and without behavioral intervention: recurring dietary and physical activity advice; no specified weight loss goal | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL 79% men | 531 (outcome analysis included 502 subjects) | T2D incidence (mean trial period: 2.5 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: IRR (95% CI)*] Placebo..................NR...................55.0.................Ref......... Metformin..............NR...................40.5........0.74 (0.65–0.81) Metformin + Lifestyle.................NR...................39.5........0.72 (0.63–0.80) ★At year 3, mean weight changes for all intervention and control groups were similar. | NR
CANOE Trial, Canada, 2010 (87) | Metformin 500 mg twice daily PLUS Rosiglitazone 2 mg twice daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL | 207 | T2D incidence (median trial period: 3.9 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3.9-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR......................39.4................Ref.......... Metformin + Rosiglitazone.........NR.....................13.6.........0.31 (0.17–0.58) ★Weight change was nonsignificant in both groups. | NR
Thiazolidinedione Medication Interventions
TRIPOD Study, U.S., 1998 (268) | Troglitazone 400 mg daily | Personal history of gestational diabetes in past 4 years Hispanic women only 70% with IGT | 266 (236 included in analysis) | T2D incidence (median trial period: 2.5 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo.................NR...................33.1.................Ref.......... Troglitazone..........NR...................17.1........0.45 (0.25–0.83) | During 8 months of follow-up after stopping troglitazone, 15% of placebo and 2.3% of troglitazone subjects who remained at risk had T2D confirmed; difference NS; low sample size (269).
DPP, U.S., 2005 (86) | Troglitazone 400 mg daily | FPG 95–125 mg/dL AND IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥24 kg/m^2^ (≥22 kg/m^2^ if Asian) | 1,167 (585 troglitazone; 582 placebo) | T2D incidence (median trial period: 0.9 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 1-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo.................12.0................14.5...................Ref......... Troglitazone............3.0..................3.1..........0.25 (0.11–0.52) ★Troglitazone HR 0.25 (p<0.001) compared to placebo ★Troglitazone arm of the DPP was stopped prematurely due to safety concerns. | During 3 years of follow-up after stopping troglitazone, rates of additional new T2D events were nearly identical between troglitazone and placebo groups.
DREAM Study, International, 2006 (270,271) | Rosiglitazone 8 mg daily | FPG 110–125 mg/dL OR IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL 29% had both IGT+IFG | 5,269 | T2D incidence (median trial period: 3.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR..................25.0.................Ref........... Rosiglitazone.........NR..................10.6.........0.38 (0.33–0.44) ★2x2 factorial design with no significant interaction effect between ramipril and rosiglitazone ★HRs did not differ among subgroups with baseline IFG, baseline IGT, or combined IFG+IGT. ★At final visit, mean weight increased 2.2 kg more with rosiglitazone than placebo (p<0.001). | During 71 days of follow-up after stopping rosiglitazone, an additional 10.5% of rosiglitazone and 9.8% of placebo subjects who remained at risk had T2D confirmed; difference NS (111).
CANOE Trial, Canada, 2010 (87) | Rosiglitazone 2 mg twice daily PLUS Metformin 500 mg twice daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL | 207 | T2D incidence (median trial period: 3.9 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3.9-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR...................39.4..................Ref......... Metformin + Rosiglitazone.........NR...................13.6..........0.31 (0.17–0.58) ★Weight change was nonsignificant in both groups. | NR
ACT NOW Trial, U.S., 2011 (272) | Pioglitazone 45 mg daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL AND FPG 95–125 mg/dL BMI ≥25 kg/m^2^ (≥22 kg/m^2^ if Asian) | 602 | T2D incidence (median trial period: 2.4 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR.................23.7.................Ref............ Pioglitazone...........NR...................6.8..........0.28 (0.16–0.49) ★ Weight increased 3.2 kg more in the pioglitazone group (p<0.001). ★ 36% of subjects assigned to pioglitazone remained taking a 30 mg dose due to weight gain at higher dose. | During 11.4 months of follow-up after stopping pioglitazone, an additional 12.3% of placebo and 11.2% of pioglitazone subjects who remained at risk had T2D confirmed; difference NS: HR 0.84 (95% CI 0.42–1.66) (273).
Angiotensin-Converting Enzyme (ACE) Inhibitor and Angiotensin Receptor Blocker (ARB) Medication Interventions
DREAM Study, International, 2006 (270,271) | Ramipril 15 mg daily | FPG 110–125 mg/dL OR IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL 29% had both IGT+IFG | 5,269 | T2D incidence (median trial period: 3.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR.................18.5.................Ref........... Ramipril.................NR.................17.1.........0.91 (0.80–1.03) ★2x2 factorial design with no significant interaction effect between ramipril and rosiglitazone ★At final visit, mean weight increased 2.2 kg more with rosiglitazone than placebo (p<0.001). | NR
NAVIGATOR Trial, International, 2010 (274,275) | Valsartan 160 mg daily With and without nateglinide 60 mg three times daily All participants received a moderate intensity lifestyle intervention. | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL AND FPG 95–126 mg/dL ≥1 cardiovascular risk factor or disease | 9,306 | T2D incidence (median trial period: 5.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 5-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo.................9.0...................36.8................Ref............. Valsartan...............7.7...................33.1.........0.86 (0.80–0.92) ★Nateglinide: HR 1.07 (95% CI 1.00–1.15) compared to placebo; 2x2 factorial design with no significant interaction with valsartan effect (p=0.53) ★Moderate or severe hypoglycemia occurred in 2.5% of placebo and 5.1% of nateglinide subjects. | NR
Intestinal Alpha-Glucosidase Inhibitor Medication Interventions
STOP-NIDDM, International, 2002 (85) | Acarbose 100 mg three times daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL AND FPG 100–139 mg/dL BMI 25–40 kg/m^2^ | 1,429 (1,368 included in outcome analysis) | T2D incidence (mean trial period: 3.3 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3.3-yr CIR (%).]..[underlined: HR (95% CI)*] Placebo..................12.1..................41.5.................Ref........... Acarbose................10.1..................32.4.........0.75 (0.63–0.90) ★Weight loss was 0.8 kg (95% CI 0.0–1.5) greater with acarbose. ★19% of acarbose and 5% of placebo subjects discontinued treatment for adverse effects (most gastrointestinal). | During 3 months of follow-up after stopping acarbose, 10.6% of placebo and 15.4% of acarbose subjects had T2D confirmed; difference NS: RR 1.46 (95% CI 0.90–2.36).
Voglibose Trial, Japan, 2009 (276) | Voglibose 0.2 mg three times daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL AND A1C <6.5% | 1,780 (1,778 included in outcome analysis) | T2D incidence (mean trial period: 0.96 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 0.9-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo.................NR....................9.4....................Ref........... Voglibose..............NR....................3.6.............0.60 (0.43–0.82) ★Treatment was discontinued per protocol in 67% of voglibose subjects who were normoglycemic at a follow-up visit. | NR
ACE Trial, China, 2017 (277) | Acarbose 50 mg three times daily | IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL Existing coronary heart disease Age ≥50 yrs 73% male | 6,522 | T2D incidence (mean trial period: 4.4 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 4.4-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................3.8...................15.8..................Ref........... Acarbose................3.2...................13.3..........0.82 (0.71–0.94) ★49% of acarbose groups discontinued medication (median time on treatment overall 3.0 years). ★Difference in the frequency of significant gastrointestinal adverse events was NS. | NR
Pancreatic Lipase Inhibitor Medication Interventions
Orlistat 3-Trial Meta-Analysis, International, 2000 (104) | Orlistat 120 mg three times daily All participants were provided a weight loss dietary prescription at each study visit. | Pooled analysis of weight loss trials; subgroup without baseline T2D BMI 30–43 kg/m^2^ No diabetes by baseline OGTT: IGT (19%); NGT (81%) | 642 (120 IGT; 522 NGT) | T2D incidence (mean trial period: 1.6 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 2-yr I (%)]...[underlined: RR (95% CI)*] Placebo..................NR................2.3...............Ref............ Orlistat...................NR................0.6........0.25 (0.05–1.21) ★After a mean follow-up of 83 weeks, mean weight loss with orlistat was 2.9 kg more than with placebo. | NR
XENDOS Study, Sweden, 2004 (105) | Orlistat 120 mg three times daily All participants were provided a weight loss dietary prescription at each study visit. | BMI ≥30 kg/m^2^ No diabetes by baseline OGTT: IGT (21%); NGT (79%) Age 30–60 yrs | 3,305 (outcome analysis included 3,277 subjects) | T2D incidence (trial period: 4.0 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 4-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR..................9.0..................Ref............ Orlistat...................NR..................6.2...........0.63 (0.46–0.86) ★Greatest effect in subgroup with baseline IGT: 4-yr CIR 18.8% placebo vs. 28.8% orlistat; HR 0.55 (p=0.002) ★Mean weight loss with orlistat was 4.4 kg greater at 1 year and 2.7 kg greater at 4 years than with placebo. | NR
Combination Bariatric Pharmacotherapy
CONQUER Trial, 93 U.S. centers, 2011 (107) | Phentermine 7.5 mg plus Topiramate 46 mg ER once daily OR Phentermine 15 mg plus Topiramate 92 mg ER once daily All participants were provided with reduced calorie dietary advice at each study visit. | Subgroup of CONQUER weight-loss trial BMI 27–45 kg/m^2^ IFG or IGT (75%) | 2,092 participants without diabetes at baseline | T2D incidence (trial period: 56 weeks) ....................[underlined: Rate (/100 PY)]...[underlined: 1-yr CIR (%)]...[underlined: IRR (95% CI)*] Placebo..................4.5..................NR...................Ref............ Phen/TPM 7.5/46 mg...............3.1..................NR...........0.69 (0.32–1.38) Phen/TPM 15/92 mg................1.9..................NR...........0.42 (0.20–0.81) ★Mean weight loss at 56 weeks was 6.0% greater with Phen/TPM 7.5/46 than with placebo and 8.2% greater with Phen/TPM 15/92 than with placebo. | NR
Glucagon-Like Peptide-1 (GLP-1) Receptor Agonist Medication Interventions
SCALE Trial, International, 2017 (93) | Liraglutide 3.0 mg daily All participants were provided with monthly counseling for dietary calorie restriction and to increase physical activity. | Subgroup of SCALE weight-loss trial A1C 5.7%–6.4% OR FPG 100–125 mg/dL BMI ≥30 kg/m^2^ OR BMI ≥27 kg/m^2^ with either dyslipidemia or hypertension | 2,254 (2,210 included in analysis) | T2D incidence (trial period: 3.1 yr) ....................[underlined: Rate (/100 PY)]...[underlined: 3.1-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR....................11.0.................Ref.......... Liraglutide.............NR......................3.0..........0.21 (0.13–0.34) ★HR 0.34 (95% CI 0.22–0.53) in worst-case sensitivity analysis for lost to follow-up ★Mean weight loss at 160 weeks was 4.3% greater with liraglutide than with placebo. Note: all participants in both treatment arms received monthly diet and activity counseling. | When retesting 12 weeks after stopping liraglutide, an additional 0.3% of placebo and 0.6% of liraglutide subjects had T2D confirmed; difference NS.
SELECT Trial, International, 2024 (94) | Semaglutide 2.4 mg once weekly | BMI ≥27 kg/m^2^ plus established cardiovascular disease No T2D at baseline Age ≥45 yrs 66% had A1C 5.7%–6.4% | 17,604 (17,594 included in analysis) | T2D incidence (mean trial period: 3.4 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3-yr CIR (%)]...[underlined: HR (95% CI)*] Placebo..................NR..................6.9..................Ref........... Semaglutide...........NR..................1.5............0.27 (0.24–0.31) ★Diabetes defined only by A1C ≥6.5% ★HR 0.23 (95% CI 0.19–0.26) for subgroup with baseline A1C 6.0%–6.4% ★Mean weight loss at 65 weeks was 0.9% with placebo and 9.7% with semaglutide (reportedly maintained through 156 weeks). | NR
SURMOUNT-1 for diabetes prevention, International, 2024 (95) | Tirzepatide once weekly Three different dose arms: 5 mg once weekly 10 mg once weekly 15 mg once weekly All participants were provided with recurring counseling for dietary calorie restriction and to increase physical activity. | Subgroup of SURMOUNT-1 Trial A1C 5.7%–6.4% OR FPG 100–139 mg/dL OR IGT: 75 g, 2-hr plasma glucose 140–199 mg/dL BMI ≥30 kg/m^2^ OR BMI ≥27 kg/m^2^ with obesity-related complication | 1,032 | T2D incidence (trial period: 3.4 yrs) ....................[underlined: Rate (/100 PY)]...[underlined: 3.4-yr CIR (%).]..[underlined: HR (95% CI)*] Placebo..................NR...................13.3..................Ref........... Tirzepatide.............NR....................1.3............0.07 (0.0–0.1) ★Mean weight loss at 176 weeks was 1.3% with placebo and 12.3%, 18.7%, and 19.7% with tirzepatide doses of 5 mg, 10 mg, and 15 mg, respectively. | When retesting 17-weeks after stopping tirzepatide, an additional 1.0% of placebo and 1.6% of tirzepatide subjects who remained at risk of T2D had T2D confirmed, difference NS; the treatment-related HR (overall) after stopping tirzepatide remained significant (HR 0.12).

This table has been adapted and updated from Diabetes in America, 3rd ed., Chapter 38: Prevention of Type 2 Diabetes (1). It includes randomized controlled trials evaluating medication or lifestyle interventions, in which (1.) interventions were directly administered or closely monitored by study personnel and (2.) incident type 2 diabetes was a primary outcome or component of a composite primary outcome, such as diabetes or death, and that outcome was assessed by a glycemic test to identify biological progression to type 2 diabetes, rather than simply a clinical diagnosis. The primary outcomes for SCALE, SELECT, and SURMOUNT were weight related, but each study was designed with sufficient sample size and rigorous outcome ascertainment to study incident type 2 diabetes as a prespecified secondary outcome, so they are included here. Within each intervention category, trials are listed chronologically, in order of the year of the first publication of results. Medication interventions of interest were those with the potential to improve insulin sensitivity directly or indirectly through weight loss or both. The Bedford study was not included in this update because the trial did not include diabetes as a primary outcome and sample sizes were low; the NAVIGATOR study was included not because of the meglitinide arm but because inhibition of the renin-angiotensin-aldosterone system by medications such as ACE inhibitors is believed to improve insulin sensitivity. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; ACE, Acarbose Cardiovascular Evaluation trial; ACT NOW, Actos Now for Prevention of Diabetes; BMI, body mass index in units of kg/m^2^; CANOE, Canadian Normoglycemia Outcomes Evaluation trial; CI, confidence interval; CIR, cumulative incidence rate (cumulative event percentage corrected for person-time); DPP, Diabetes Prevention Program; DREAM, Diabetes Reduction Assessment With Ramipril and Rosiglitazone Medication trial; ER, extended release; FPG, fasting plasma glucose; GIP, glucose-dependent insulinotropic polypeptide; GLP-1, glucagon-like peptide-1; HR, hazard rate; I, incidence (cumulative events / N analyzed); IFG, impaired fasting glucose; IGT, impaired glucose tolerance; IRR, incidence rate ratio; NAVIGATOR, Nateglinide and Valsartan in Impaired Glucose Tolerance Outcomes Research trial; NGT, normal glucose tolerance; NR, not reported; NS, not statistically significant at the <0.05 threshold; OGTT, oral glucose tolerance test; OR, odds ratio; PY, person-years; RR, risk ratio; SELECT, Semaglutide Effects on Cardiovascular Outcomes in People With Overweight or Obesity; STOP-NIDDM, Study to Prevent NIDDM; SURMOUNT-1, A Study of Tirzepatide in Participants With Obesity or Overweight; T2D, type 2 diabetes mellitus; TRIPOD, Troglitazone in Prevention of Diabetes trial; XENDOS, XENical in the prevention of Diabetes in Obese Subjects.

* Effects expressed as event rates per 100 person-years (100 PY) of follow-up time and hazard ratios (HR), reflecting the ratio of the active treatment group event rate to control group event rate, where the control for medication comparisons was a blinded placebo medication and control for a lifestyle intervention was typically very brief healthy lifestyle advice or “usual care.” When hazard rates per person-time were not directly reported, but events were reported for each assessment period during the study, effects are expressed as cumulative incident rates (CIR) for the entire intervention period (as displayed), along with incident rate ratios (IRR), reflecting the ratio of the active treatment CIR to the control group CIR. When events were not reported for each assessment period, but total events over the entire study period were reported, effects are expressed as a cumulative incidence (%), along with risk ratios (RR), reflecting the ratio of the active treatment cumulative incidence (I) to the control group cumulative incidence. Weight change effects are included when reported because weight loss mediates incident type 2 diabetes risk by improving insulin sensitivity.

† Removal of treatment refers to the findings of studies in which subjects were asked to return for type 2 diabetes retesting after assigned interventions were discontinued at end of the trial. For medication treatments that directly lower blood glucose (e.g., biguanides, alpha-glucosidase inhibitors, thiazolidinediones, meglitinides, sulfonylureas, and GLP-1 or GIP receptor agonists), excess cases of incident type 2 diabetes identified within a few weeks to months of treatment removal typically reflect subjects who had already undergone metabolic development of type 2 diabetes but whose diagnosis had been masked while still taking an acute glucose-lowering medication; excess cases of incident type 2 diabetes identified after this period most typically result from gradual weight regain from treatments that had promoted weight loss. In the unique case of the DPP, active behavioral treatment was continued after the initial intervention trial at a slightly lower intensity for lifestyle subjects, while placebo subjects were offered the same active intervention. This treatment switch rather than removal caused two simultaneous effects: acceleration of type 2 diabetes event rates in lifestyle subjects with gradual weight regain PLUS slowing of event rates in placebo subjects due to effects of the newly introduced lifestyle intervention.

‡ Lifestyle interventions are classified with respect to the frequency of intervention contact to provide behavioral support: intensive (recurring at least monthly); moderate (recurring but less than monthly but more than annually); brief (annual or less).

SOURCE: References are listed within the table.

TABLE 3.

Relative Characteristics of Interventions for Type 2 Diabetes Prevention

INTERVENTION | BURDEN OF ENGAGING IN TREATMENT* | EFFECT ON NEED FOR MEDICATION TAKING | EFFECT ON VISCERAL ADIPOSITY | EFFECT ON INSULIN SENSITIVITY | EFFECT ON PRESERVING Β-CELL FUNCTION^†^ | RELATIVE RISK FOR SIDE EFFECTS OR HARM^‡^ | DIRECT TREATMENT COST PER-PERSON IN FIRST YEAR^§^
Behavioral interventions to increase physical activity | ↑↑↑ | – | – /↓ | ↑ | Unclear | – /↑ | Depends on the hours of professional support
Behavioral interventions to improve diet composition | ↑↑↑ | – / ↓ | ↓ | ↑ Proportional to weight loss | ↑ Proportional to weight loss | Unlikely | Depends on the hours of professional support
Intensive, multicomponent lifestyle interventions | ↑↑↑↑ | ↓ | ↓↓ | ↑ Proportional to weight loss and activity | ↑ Proportional to weight loss | – /↑ | $606–$2,139
Glucose-lowering medications with modest weight loss effects (e.g., acarbose; metformin) | – | ↑ | ↓ | ↑ (acute effect of metformin) ↑ Proportional to weight loss | ↑ Proportional to weight loss | ↑ | $292–$984
Bariatric medications without glucose-lowering effects (e.g., orlistat, phentermine/ topiramate, naltrexone/ bupropion) | ↑ | ↑ | ↓↓ | ↑ Proportional to weight loss | ↑ Proportional to weight loss | ↑ | $3,359–$9,036
GLP-1 receptor agonists | ↑ | ↑ | ↓↓↓ | ↑ Proportional to weight loss | ↑ Proportional to weight loss | ↑ | $15,649–$19,680
Bariatric surgery | ↑ | ↓↓ | ↓↓↓↓↓ | ↑ Proportional to weight loss | ↑ Proportional to weight loss | ↑↑↑ | $16,588–$18,397
Thiazolidinediones | – | ↑ | – / ↓ | ↑↑ (acute effect) | Unlikely | ↑↑ | $2,158

Arrows indicate whether the characteristic increases or decreases after treatment; more arrows represent greater effects relative to the other treatments listed. GLP-1, glucagon-like peptide-1.

* Burden of engaging in treatment reflects the magnitude and duration of demands placed on an individual to engage in full treatment (e.g., self-monitoring and self-regulation of diet and physical activity; effort to overcome physical, social, and emotional barriers to healthful eating and daily physical activity; ongoing medication adherence; attending visits for behavioral counseling, laboratory medication monitoring, and follow-up medical care).

† Indicates the β-cell secretory response when stopping treatment after the full treatment effect has been achieved (e.g., not attending lifestyle coaching visits; not exercising for >72 hours; not taking a medication for >5 half-lives or until no longer bioavailable).

‡ Risk of side effects or harms relative to other listed treatments (e.g., injury, medication adverse effects; postsurgical complications; sarcopenia causing frailty or osteopenia; nutritional deficiencies)

§ Direct medical cost of taking treatment for one year, scaled to 2025 USD by inflating source data on costs for the consumer price index for medical care (278); intensive lifestyle intervention costs are from systematic reviews of a range of program formats (42); bariatric surgery costs are based on Medicare rates for surgery and immediate post-acute care (279); all medications costs are June 2025 average retail prices (non-discounted), as published by www.goodrx.com (41).

SOURCE: References are listed within the footer.