# Diabetes in Older Adults

## Summary

Meeting the care needs of older adults (age ≥65 years) living with diabetes is a significant and growing public health challenge in the United States. The steady growth of this population is due to the aging of the U.S. population coupled with a high prevalence of diabetes. In 2023, the prevalence of diabetes was 20.5% for adults age ≥65 years, and nearly half (47%) of adults living with diabetes were in this age group. Comorbidities that can result from diabetes are also prevalent among older adults and include heart disease, stroke, and kidney disease. Geriatric syndromes, such as cognitive impairment, falls, urinary incontinence, frailty and sarcopenia, disability, sensory impairment, polypharmacy, social isolation, and loneliness are present in many older adults with diabetes as well. As a result, the older adult population with diabetes exhibits great heterogeneity in duration of diabetes, complications, comorbidity profiles, and geriatric syndromes. The clinical appreciation of this heterogeneity has led to the development of classification approaches and specialized diabetes care guidelines to individually tailor diabetes care, drug selection, and treatment goals.

The evidence for lifestyle (diet and exercise) and pharmacologic interventions for preventing and managing diabetes in older adults has expanded dramatically over the past three decades. New glucose-lowering medications, such as glucagon-like peptide-1 receptor agonists (GLP-1 RAs), dual GLP-1/glucose-dependent insulinotropic polypeptide receptor agonists (GLP-1/GIP RAs) and sodium-glucose cotransporter-2 (SGLT2) inhibitors, have transformed diabetes management for older adults. Diabetes technologies, such as continuous glucose monitoring devices, can be a valuable tool to promote safety for older adults with diabetes who use insulin.

The costs of diabetes care in older adults continue to grow, due to an expanding population, high rates of obesity, rising drug prices, and the availability of new, more expensive drugs. In 2022, the direct medical costs of diabetes care for older adults were estimated to be $205 billion per year. New policies, such as the Inflation Reduction Act which permits Medicare to negotiate drug prices, may help to ensure access to newer glucose-lowering drugs for older adults in the United States. Fundamentally, innovative approaches to both preventing and managing diabetes in older adults are desperately needed to ensure a more sustainable future.

## Introduction

The physiologic hallmarks of type 2 diabetes are increased insulin resistance and impaired insulin secretion (1). Diabetes and aging are linked, as diabetes can accelerate aging and aging leads to changes in glucose metabolism (2). Adiposity, sarcopenia (decreased muscle mass and function), physical inactivity, and inflammation are also related to both aging and diabetes and lead to impaired pancreatic β-cell insulin secretion and tissue sensitivity to insulin in older adults (3,4,5,6,7,8). Although type 2 diabetes is the predominant cause of diabetes in older adults, the number of older adults with type 1 diabetes is also growing (9). Type 1 diabetes is characterized by autoimmune attack on pancreatic β-cells, resulting in the destruction of insulin production (10). The clinical course of older adults with diabetes is often complicated by concomitant chronic diseases (e.g., hypertension) and geriatric syndromes (e.g., cognitive impairment) (11) that can interact with their diabetes or their diabetes management and accelerate the progression of diabetes complications (e.g., retinopathy). This article provides a comprehensive review of the current state of diabetes among older adults in the United States and updates the Diabetes in America, 3rd edition, chapter Diabetes in Older Adults (12).

## Sources and Limitations of National Data on Diabetes in Older Adults

The National Health Interview Survey (NHIS) and the National Health and Nutrition Examination Survey (NHANES) provide cross-sectional snapshots of the nation’s health among community-dwelling adults. These data sets were analyzed separately to evaluate characteristics of diabetes in older adults; results are presented in the figures, tables, and appendices. A limitation of both data sets is that they do not include individuals living in institutions, such as nursing homes or assisted living facilities.

The NHIS is a cross-sectional household interview survey that uses a complex sampling design and has been conducted continuously since 1957. In the NHIS 2000–2023 survey cycles, diabetes was determined among participants age ≥60 years who answered “yes” to the following question: “(If female, other than during pregnancy) Have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” and includes both type 1 and type 2 diabetes. Since diabetes is self-reported, undiagnosed diabetes cannot be determined in the NHIS. In this article, data from the NHIS were analyzed to determine trends in the prevalence of diabetes among older adults and the prevalence of associated comorbidities and geriatric syndromes. Although the questionnaire items in NHIS are comprehensive, a limitation is that the data are self-reported.

The NHANES is a cross-sectional, national probability sample that has been conducted periodically since 1971 and continuously since 1999. This article utilizes NHANES data collected from individuals age ≥60 years for the period 2017–2023 to assess glycemic status (diagnosed diabetes, undiagnosed diabetes, prediabetes, normal glycemia) and associated comorbidities. Due to the COVID-19 (coronavirus disease of 2019) pandemic, there is an 18-month data gap between March 2020 and August 2021. Participants self-reported their diagnosed diabetes status based on the question “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Self-reported diagnosed diabetes includes both type 1 and type 2 diabetes. An advantage of the NHANES is that the survey includes a health exam in a mobile examination center where laboratory measures are collected. Thus, the NHANES has laboratory information on glycated hemoglobin (A1C) and fasting plasma glucose to determine undiagnosed diabetes, prediabetes, and normal glycemia. In this article, data from the NHANES were analyzed to determine diabetes status and the prevalence of associated comorbidities and geriatric syndromes among older adults.

### Statistical Methods

All results from national surveys are statistically weighted to produce estimates that are nationally representative of the noninstitutionalized U.S. population. The weighted standard errors for estimates are shown in the tables. In cases where the sample size is small and the results may be imprecise, the relative standard error (RSE = [SE/estimate]*100) is provided in tables. If RSEs are >50%, the results are not shown.

## Demographic Characteristics of Older Adults With Diabetes

### Differentiating Between Diabetes Types

The absolute number of older adults with type 1 diabetes is growing, both due to increased longevity of individuals diagnosed at younger ages and a rising number of new diagnoses in older adults (9). The prevalence of type 1 diabetes in adults age ≥65 years in the United States grew from 0.42% in 1990 to 0.60% in 2019 based on an analysis of data from the Global Burden of Disease Study, which uses multiple data sources including hospital data and publicly available population data (13). An analysis of NHIS 2019–2022 data found that the estimated prevalence of type 1 diabetes among adults age ≥65 years was 0.53% (based on self-report of type 1 diabetes) (14). The incidence rate for type 1 diabetes in adults age 60–64 years was 29.2 cases per 100,000 person-years according to a longitudinal study that utilized the Clinformatics Data Mart Database for years 2001–2015 (15).

Differentiating between type 1 and type 2 diabetes in older adults can be challenging. People are not always aware of what type of diabetes they have (16), and autoantibody and C-peptide levels (biomarkers often used to differentiate type 1 from type 2) may change with age and are not routinely measured (9,17). Some older adults with diabetes also have latent autoimmune diabetes in adults (LADA), a form of autoimmune diabetes that develops slowly in adults and is often initially misdiagnosed as type 2 diabetes, or monogenic diabetes, where a genetic mutation impacts β-cell activity.

Clinically, the heterogeneity of diabetes in older adults presents challenges for diagnosis, as well as for management. Older adults with diabetes may have different pathophysiology of their diabetes and different comorbidities and risk factors based on their age at diagnosis. Interest has been growing in developing new diabetes classification schemes that reflect this variation. These classification schemes (based on such variables as glutamate decarboxylase antibodies, age at diagnosis, body mass index [BMI], A1C, estimates of β-cell function, and insulin resistance) may more accurately predict risks of diabetes complications and may allow for individualized treatment plans based on individuals’ characteristics and risks (18). The clinical heterogeneity of older adults with diabetes is discussed in more detail below.

### Population Size and Prevalence of Diabetes in Community Settings

According to new analyses of NHIS 2022–2023 data conducted for Diabetes in America, 11.6 million adults age ≥65 years had a self-reported diagnosis of diabetes (Table 1). The overall prevalence of diagnosed diabetes in the population age ≥65 years was 20.3%. Compared to adults ages 60–69 and ≥80 years, those age 70–79 years had the highest prevalence of diagnosed diabetes (21.7%). Men had a higher prevalence of diagnosed diabetes than women for every age group (e.g., at age ≥80 years, 22.2% for men vs. 16.9% for women).

The prevalence of diabetes among older adults has been relatively stable since 2010 with some differences by age groups. The prevalence of diagnosed diabetes among older adults age ≥65 years based on the NHIS was 21.4% in 2010 and 20.5% in 2023, which represents a 4.2% relative decrease (Figure 1, Appendix Table A1). Adults age 60–69 years saw a relative decrease in prevalence of diagnosed diabetes of 5.7%, and adults age 70–79 years had a relative decrease in prevalence of 10.7%. Among adults age ≥80 years, there was a relative increase in prevalence of 2.2%.

Although the prevalence of diagnosed diabetes has remained relatively stable among older adults over time, the absolute number of older adults living with diabetes in the United States has increased steadily. Based on data from the NHIS 2010–2023, the number of adults age ≥65 years with diagnosed diabetes grew by nearly 50%, from an estimated 8.28 million to 11.9 million (Figure 2, Appendix Table A2). The relative rate of increase was highest for those age 70–79 years (1.45-fold increase), followed by adults ages ≥80 years (1.31-fold increase) and 60–69 years (1.27-fold increase).

Not only has there been an increase in the absolute number of older adults living with diabetes, but there has also been a substantial increase in the percentage of adults with diabetes who are age ≥65 years. From 2010 to 2023, the percentage of adults with self-reported diagnosed diabetes who were age ≥65 years rose from 39.5% to 47.1%, representing a 19.2% relative increase (Table 2). This increase reflects the demographic shift in the overall U.S. population, as the percentage of Americans age ≥65 years grew from 13% to 16.8% from 2010 to 2020 (19). Thus, as more of the adult population are now age ≥65 years, more of the adult population with diabetes are also age ≥65 years. Based on estimates from the NHIS 2010–2023, the percentage of adults with diabetes age 60–69 years grew from 26.9% to 28.4% (1.06-fold increase). The percentage of adults with diabetes age 70–79 years grew from 19.0% to 23.0% (1.21-fold increase), and the percentage of adults with diabetes age ≥80 years grew from 8.9% to 9.6% (1.08-fold increase).

In the NHANES 2017–2023, 7.0% of adults age ≥65 years were unaware that they had diabetes, as defined by abnormal laboratory test results (A1C ≥6.5% [≥48 mmol/mol] or fasting plasma glucose ≥126 mg/dL [≥6.99 mmol/L]) (Table 3). This represents a slight decrease from NHANES 2005–2010 data, when the prevalence of undiagnosed diabetes among older adults was 7.8% according to A1C or fasting plasma glucose (12). Adults age ≥80 years had a higher prevalence of undiagnosed diabetes than adults ages 60–69 and 70–79 years based on either abnormal laboratory criterion.

Prediabetes is defined in the NHANES data by A1C 5.7%–<6.5% (39–<48 mmol/mol) or fasting plasma glucose 100–<126 mg/dL (5.55–<6.99 mmol/L). However, A1C increases with age, and this increase is not always associated with abnormal glucose homeostasis (20). Additionally, in an analysis of 3,412 older adults from the Atherosclerosis Risk in Communities Study (2011–2013), fewer than 12% of older adults progressed from prediabetes to diabetes within 6.5 years of follow-up (21). Reversion to normoglycemia or death were far more common than developing diabetes, making the prognostic significance of prediabetes in older adults less clear. Based on the NHANES 2017–2023, 53.9% of adults age ≥65 years had prediabetes (Table 3). In comparison, 46.4% of older adults had prediabetes in the NHANES 2005–2010 data (12). The prevalence of prediabetes was quite similar across the stratified age groups in the NHANES 2017–2023 for adults ages 60–69, 70–79, and ≥80 years.

### Race/Ethnicity

Based on new analyses of data from the NHIS 2022–2023, 30.1% of non-Hispanic Black, 31.4% of Hispanic, and 29.6% of non-Hispanic Asian adults age ≥65 years had diabetes compared to 16.9% of White adults age ≥65 years (Table 4). Accordingly, 14.3% of older adults with diabetes were non-Hispanic Black and 14.8% were Hispanic. In comparison, older adults without diabetes were 8.4% non-Hispanic Black and 8.2% Hispanic, highlighting an increased burden of diabetes in non-Hispanic Black and Hispanic adults (Table 5). Compared to NHIS 2009–2010 data (12), the proportions of older adults with diabetes who are non-Hispanic Black and Hispanic have grown over time.

With increasing age, a lower proportion of older adults with diabetes were non-Hispanic Black (11.3% of adults age ≥80 years vs. 16.9% of adults age 60–69 years) or Hispanic (12.0% of adults age ≥80 years vs. 16.5% of adults age 60–69 years) (Table 6). This change in demographic composition with increasing age may be related to life expectancy variations by race (22).

### Population Size and Prevalence of Diabetes in Residents of Long-Term Care Facilities

Individuals living in long-term care facilities have high rates of diabetes, and there are special considerations for this population. Older adults in long-term care facilities face challenges related to irregular eating habits, altered cognition, medication errors during transitions of care, variable levels of social support, impaired mobility and risk of bedsores, and a tendency for facilities to use sliding scale insulin alone for glycemic management (23,24).

The National Post-acute and Long-term Care Study (NPALS) includes data from National Center for Health Statistics surveys of long-term care providers, as well as administrative data from the Centers for Medicare and Medicaid Services (CMS). In the NPALS 2020, 64.5% of long-term care hospital residents, 34.5% of nursing home residents, and 16.9% of residential care community residents had diabetes (25). Long-term care hospitals serve individuals who require hospital-level care for longer periods of time, while nursing homes provide skilled nursing and daily living support, and residential care communities provide primarily daily living support. Although these statistics do not distinguish between older and younger adults, the majority of individuals in these long-term care facilities were age ≥65 years in the study. In the NPALS 2013–2014 (at the time called the National Study of Long-Term Care Providers [NSLTCP], as it did not include long-term care hospitals and inpatient rehabilitation facilities), 32.4% of nursing home residents and 16.9% of residential care community residents had a diagnosis of diabetes. This represents a 6.5% relative increase in diabetes prevalence in nursing homes from 2013–2014 to 2020 and no change in the prevalence of diabetes in residential care communities (26).

## Duration of Diabetes

Older adults with diabetes vary greatly with regard to the duration of their diabetes. In the NHIS 2022–2023, the majority of older adults had diabetes durations ≥10 years. Among adults age 60–69 years, the mean duration of diabetes was 14.2 years (standard error 0.3) and 59.3% had a diabetes diagnosis for ≥10 years (Figure 3, Appendix Table A3). The mean duration of diabetes for adults age 70–79 years was 17.4 years (standard error 0.4) and 70.7% had a diabetes duration of ≥10 years. Among adults age ≥80 years, the mean duration of diabetes was 22.3 years (standard error 0.7) and 78.6% of the group had a diabetes diagnosis for ≥10 years. A longer duration of diabetes translates into higher risks of diabetes complications, which adds to the heterogeneity of this population.

## Comorbidities of Diabetes

Older adults with diabetes are at increased risk for concomitant cardiovascular risk factors, diabetes complications, geriatric syndromes, and comorbid diseases. Compared to the population without diabetes, older adults with diabetes have a higher risk of blindness, renal failure, coronary heart disease, and stroke (27). Additionally, older adults with diabetes are at higher risk for geriatric syndromes, including falls (28), osteoporosis (29), urinary incontinence (30), chronic pain (31), depression (32), cognitive impairment and dementia (33), frailty/sarcopenia (34,35), impairment in functional status (36), and polypharmacy (37). Geriatric syndromes are important considerations for older adults with diabetes because they can have a devastating effect on quality of life and the feasibility of some diabetes management strategies. In addition, older adults with diabetes frequently have multimorbidity, which increases the risks of polypharmacy and drug interactions. A description of these comorbidities is provided below.

### Overweight and Obesity

Older adults with diabetes have a high prevalence of overweight (defined by BMI 25–<30 kg/m^2^, except for non-Hispanic Asian adults where overweight is defined as BMI 23–27.4 kg/m^2^) and obesity (defined by BMI ≥30 kg/m^2^, except for non-Hispanic Asian adults where obesity is defined as BMI ≥27.5 kg/m^2^). NHANES 2017–2023 data showed that 88.3% of adults age ≥65 years with diabetes had overweight or obesity compared to 73.7% of adults age ≥65 years without diabetes (Figure 4, Appendix Table A4). Among adults age ≥65 years, 53.9% of those with diabetes had obesity compared to 36.5% of those without diabetes, while 34.4% with diabetes had overweight compared to 37.2% of those without diabetes. According to the NHIS 2022–2023, the rates of obesity among older adults with diabetes decreased with increasing age, as 55.8% of adults age 60–69 years had obesity compared to 47.5% of adults age 70–79 years and 35.8% of adults age ≥80 years. The proportion of adults with overweight increased slightly with age. Of adults age 60–69 years with diabetes, 32.3% had overweight compared to 36.6% of adults age 70–79 years and 37.9% of adults age ≥80 years (Figure 5, Appendix Table A5). Additional information about overweight and obesity in individuals with diabetes can be found in the Diabetes in America article Obesity Management for the Treatment of Type 2 Diabetes (38).

### Hypertension

Hypertension is prevalent among adults with diabetes, as insulin resistance may predispose to hypertension and the vascular effects of hypertension may contribute to insulin resistance (39). In the NHANES 2017–2023, 87.6% of older adults age ≥65 years with diabetes had hypertension, defined as the presence of any one of the following: blood pressure ≥130/80 mmHg, self-report of hypertension diagnosis, or self-report of antihypertensive medication use (Table 7). The average blood pressure for older adults with diabetes was 132/70 mmHg in the NHANES 2017–2023. Nearly 10% (9.1%) of the older adults with diabetes had systolic blood pressure (SBP) levels ≥160 mmHg, and a small percentage (5.0%) had diastolic blood pressure levels ≥90 mmHg. In a new analysis of NHANES 2017–2020 data, 66.3% of adults age ≥65 years reported taking an angiotensin-converting enzyme inhibitor or angiotensin II receptor blocker, antihypertensives that have an additional benefit of preventing progression of renal disease (Table 8).

### Hyperlipidemia

According to a new analysis of data from the NHANES 2017–2023, low-density lipoprotein (LDL) cholesterol levels averaged 83 mg/dL (2.15 mmol/L) in adults age ≥65 years with diabetes (Table 7). Most older adults with diabetes had an LDL <100 mg/dL (<2.59 mmol/L; 76.8%). Additionally, over two-thirds (67.6%) of adults age ≥65 years with diabetes reported taking a statin, according to analyses of NHANES 2017–2020 data (Table 8).

### Smoking

Among adults age ≥65 years, the proportion of adults with diabetes who self-reported current smoking (8.3%) was similar to the proportion of those without diabetes (8.5%) in the NHANES 2017–2023 (Table 9). The prevalence of smoking among older adults with diabetes was greatest among the youngest age group and decreased with advancing age (60–69 years, 15.9%; 70–79 years, 7.6%; ≥80 years, 2.1%). The observation that the rate of current smoking declines with advancing age may be due to differences in survivorship associated with smoking.

### Infections

Diabetes increases the risk of infections, in part because hyperglycemia impairs immune system function (40). Older adults with diabetes are also at increased risk of infections due to immunosenescence, malnutrition, anatomic changes that increase susceptibility to infection, and high prevalence of diabetes complications (41,42). A study of NHIS and National Inpatient Sample (an all-payer hospital inpatient care database) data from 2015 found that the hospitalization rate for infections among adults age 65–74 years was over twice as high for those with diabetes compared to those without diabetes (72.9 per 1,000 people vs. 30.1 per 1,000 people). Among adults age ≥75 years, the hospitalization rates for infections were 131.7 per 1,000 adults with diabetes and 78.0 per 1,000 adults without diabetes (43).

### Cardiovascular Complications

Diabetes increases the risk of cardiovascular complications in adults, especially among older adults, as described in the Diabetes in America articles Heart Disease and Diabetes (44) and Stroke and Diabetes in Adults (45). In new analyses of the NHANES 2017–2023, the prevalences of all forms of cardiovascular complications (e.g., congestive heart failure, coronary heart disease, and stroke) were significantly higher for older adults with diabetes compared to those without diabetes (Figure 6, Appendix Table A6). The increased rate of cardiovascular complications was most pronounced for congestive heart failure and “any heart condition with angina” (“any heart condition” includes heart failure, coronary heart disease, or heart attack), which were both nearly three times more prevalent among older adults with diabetes compared to those without diabetes (14.6% vs. 5.6% for congestive heart failure and 8.0% vs. 2.9% for “any heart condition with angina”). According to NHIS 2022–2023 data, coronary heart disease was the most common cardiovascular condition and was present in 23.9% of older adults with diabetes, followed by heart attack (14.3%), stroke (12.1%), and angina (6.9%) (Figure 7, Appendix Table A7). All cardiac conditions in the NHIS were defined based on self-report of whether a physician had ever told the participant that they have coronary heart disease, heart attack, stroke, or angina. The prevalences of the reported cardiovascular complications increased with age, with adults age ≥80 years having the highest prevalences of coronary heart disease, angina, heart attack, and stroke.

### Microvascular Complications

Microvascular complications are prevalent among older adults with diabetes, according to new analyses of national data for Diabetes in America. In the NHANES 2017–2023, 17.9% of older adults with diabetes self-reported a diagnosis of retinopathy (Figure 8, Appendix Table A8). The literature suggests that self-report of diabetic retinopathy has high specificity (94%–98%) but low sensitivity (9%–42%), so the true prevalence of retinopathy may be higher (46). Additionally, in the NHIS 2022–2023, 28.8% of adults age ≥65 years living with diabetes reported trouble seeing and 1.6% reported blindness (Figure 9, Appendix Table A9). Adults with diabetes age ≥80 years had the highest rates of trouble seeing (31.8%) across the three age groups.

Moderately elevated albuminuria, a measure of protein in the urine defined by an albumin-to-creatinine ratio 30–300 mg/g (3.39–33.9 mg/mmol), was over twice as common among older adults with diabetes (28.4%) compared to those without diabetes (12.4%) in the NHANES 2017–2023 (Figure 8, Appendix Table A8). A decreased estimated glomerular filtration rate of <60 mL/min per 1.73 m^2^ (based on the Chronic Kidney Disease Epidemiology Collaboration Creatinine Equation 2021 and serum creatinine) was 62% more prevalent among older adults with diabetes compared to those without diabetes (30.9% vs. 19.1%, respectively). The Diabetes in America article Kidney Disease and Diabetes contains additional information about renal complications of diabetes (47).

Diabetes-related peripheral artery disease (PAD) is prevalent among older adults but may be decreasing over time. A study of Medicare claims data for more than 9 million participants from 2007–2019 found a 33% decrease in annual new concomitant diabetes and PAD diagnoses throughout the study, from 30 diagnoses per 1,000 people in 2007 to 20 diagnoses per 1,000 people in 2019 (48). Although all racial groups experienced a decrease in new PAD diagnoses over time, rates of diagnosis remained higher in Native American, Black, Hispanic, and Asian/Pacific Islander participants compared to White participants. PAD data are limited, as many individuals with PAD may not experience symptoms or present to medical care, resulting in likely underdiagnosis and ascertainment bias (48). Average one-year amputation rates (percent of individuals with diabetes and PAD who underwent amputation within one year) in this study rose slightly throughout the period, from 1.4% in 2007 to 1.9% in 2018. The reason for a rise in amputation rates and a decrease in new PAD diagnoses is unclear, although given that only new PAD diagnoses were analyzed, it may be that more time is needed to see a change in long-term sequelae of PAD, such as amputation.

### Geriatric Syndromes

In addition to the traditional cardiovascular and microvascular complications, the presence of diabetes is associated with an increased risk of many geriatric syndromes. Prevalence estimates of geriatric syndromes are likely underestimated since they may not fully account for conditions that are difficult to measure, such as cognitive dysfunction, depression, and frailty.

#### Cognitive Impairment and Dementia

Diabetes is associated with increased prevalence of cognitive impairment and dementia in older adults (49), as well as increased rate of progression from cognitive impairment to dementia (33,50). Cognitive impairment is also associated with hypoglycemia in a bidirectional relationship, as cognitive impairment increases the risk for future hypoglycemia (51), and past severe hypoglycemia, especially when recurrent, can increase the incidence of dementia (52). In the Study of Osteoporotic Fractures, older women with diabetes performed significantly worse on cognitive function tests compared to older women without diabetes (53). Further, after 3–6 years of follow-up, they had increased odds of major cognitive decline. Women with diabetes duration >15 years had a 57%–114% greater risk of major cognitive decline compared to women without diabetes at 3–6 years of follow-up. A cross-sectional analysis of NHANES 2011–2014 data for adults age ≥60 years found that higher A1C levels were associated with worse cognitive function scores, and cognitive impairment was more prevalent in older adults with A1C ≥8% (≥64 mmol/mol) compared to those with A1C <7% (<53 mmol/mol) (14.6% vs. 6.3%) (54).

#### Falls

Risk for injurious falls is greater among older adults with diabetes compared to their nondiabetic counterparts. The longitudinal Health, Aging, and Body Composition Study of 3,075 adults age 70–79 years found that those living with diabetes had a higher risk of falls requiring hospitalization than those without diabetes (hazard ratio [HR] 1.48, 95% confidence interval [CI] 1.12–1.95), and those taking insulin had a hazard ratio of 3.0 (95% CI 1.78–5.07) compared to those without diabetes (55). This increased risk of falls is associated with increased rates of fractures. The Study of Osteoporotic Fractures was a multicenter, longitudinal study of 9,654 older community-dwelling women that began in 1986. Over a mean follow-up of 9.4 years, diabetes was associated with an 82% increased risk of hip fracture and a 94% increased risk of proximal humerus fracture, and treatment with insulin was associated with a two times greater risk of foot fractures (56). A study in the Veterans Affairs Health System from 2000–2010 of nearly 3 million men age 65–99 years found that the presence of diabetes conferred a 22% greater risk of any clinical fracture (57).

#### Urinary Incontinence

According to Diabetes in America analyses of NHANES 2017–2023 data, urinary incontinence (defined by self-reported leakage occurring a few times a week or every day and/or night) was more prevalent in adults age ≥65 years with diabetes in comparison to those without diabetes (35.3% vs. 28.8%) (Table 10). Among those living with diabetes, urinary incontinence was nearly twice as common in older women (48.5% prevalence) than older men (24.1% prevalence). The prevalence of urinary incontinence increased with age among individuals with diabetes, from 25.8% to 34.2% and 45.8% in those ages 60–69, 70–79, and ≥80 years, respectively (Table 11). The difference by sex widened as well, with 62.3% of women with diabetes age ≥80 years reporting urinary incontinence compared to 28.1% of men with diabetes age ≥80 years.

#### Chronic Pain

Among geriatric syndromes, chronic pain is prevalent and seriously impacts health-related quality of life in older adults with diabetes (58). Additionally, older adults with diabetes are at higher risk for chronic pain compared to older adults without diabetes, possibly due to their increased risk of peripheral neuropathy (59), PAD (60), falls (55), and osteoarthritis (61).

According to new Diabetes in America analyses of data from the NHIS 2023, chronic pain was reported more frequently by adults age ≥65 years with diabetes compared to those without diabetes (Table 12). Chronic pain (reported as any pain in the past 3 months on most days or every day) was reported by 45.5% of older adults with diabetes compared to 33.5% of older adults without diabetes. Hip pain (reported as pain some days, most days, or every day in the past 3 months) was the most common pain reported by 52.6% of older adults with diabetes, followed by back pain in 42.4% of older adults with diabetes. The prevalence of any chronic pain increased slightly with age, from 45.0% to 45.4% and 47.0% in adults with diabetes ages 60–69, 70–79, and ≥80 years, respectively (Figure 10, Appendix Table A10).

#### Depression

Depression is prevalent among older adults with diabetes (62,63,64) and is associated with an increased risk of poor glycemic control (65) and worsened complications of diabetes (66). Depressive symptoms, defined as a Patient Health Questionnaire (PHQ-9) score ≥10, were almost twice as prevalent in adults age ≥65 years with diabetes compared to those without diabetes (12.2% vs. 6.2%) in a new analysis of NHANES 2017–2023 data (Table 10). The prevalence of depressive symptoms decreased slightly with age and was higher among adults with diabetes age 60–69 years (14.3%) compared to adults with diabetes age ≥80 years (10.0%) (Table 11). The relationship between diabetes and depression is discussed in the Diabetes in America article Psychosocial and Behavioral Health Among Youth and Adults With Diabetes (67).

#### Sarcopenia and Frailty

Sarcopenia describes declines in lean body mass and function commonly seen in older adults. Frailty is a broader term that encompasses sarcopenia, as well as age-associated declines in strength, endurance, balance, walking performance, and activity (68). Older adults with diabetes have a greater risk of sarcopenia (69) and frailty (1) than those without diabetes. A study of community-dwelling older women found that diabetes was associated with an increased risk of being prefrail and frail (70). Frail and prefrail states were based on five indicators: weight loss, weakness, exhaustion, slowness, and low physical activity. Frailty was defined as the presence of three or more indicators, and prefrailty as the presence of one or two indicators. Frailty also confers a greater risk of health complications and mortality. In a study of veterans age ≥65 years with diabetes, the presence of frailty was associated with a greater number of hospitalizations (HR 1.71, 95% CI 1.31–2.24) and higher mortality (HR 2.05, 95% CI 1.16–3.64) (71). An analysis of NHANES 1999–2018 data showed that sarcopenia is more prevalent among older adults with diabetes and increases with increasing age; among adults age 60–69 years, the prevalence of sarcopenia in those with diabetes was almost double the prevalence in those without diabetes (34). Older adults with diabetes also have a faster rate of muscle loss than those without diabetes. The Health, Aging, and Body Composition study found that leg muscle mass and strength (knee extension strength measured by an isokinetic dynamometer) decreased more rapidly in participants with diabetes than in those without diabetes (72).

#### Disability and Impairment in Activities of Daily Living

Diabetes substantially increases the risk of impairment in activities of daily living, as described in the Diabetes in America article Disability and Diabetes in Adults (73). This issue is particularly prominent among older adults (74,75). In an analysis of data from the Health and Retirement Study (1998–2012), adults age ≥50 years with diabetes developed disability 6–7 years earlier than adults without diabetes (76).

In the NHIS 2022–2023, disability index was measured with the Washington Group Short Set Composite Disability Indicator. Respondents who indicated “a lot of difficulty” or “cannot do at all” to at least one of the six functional domains (vision, hearing, mobility, communication, cognitive, and self-care) were considered to have any disability. New analyses of these data for Diabetes in America showed that 28.3% of adults age ≥65 years with diabetes were considered to have any disability compared to 15.8% of those without diabetes (Table 13). Similarly, having difficulty with ≥1 function (walking, self-care, using hands and fingers, or raising a 2-liter bottle) was nearly twice as common among older adults with diabetes (40.5% vs. 21.2%). Having any disability was more common with increasing age, and many functional limitations were nearly twice as prevalent in adults with diabetes age ≥80 years compared to those age 60–69 years (Table 14). Nearly half (43.0%) of adults age ≥80 years had any disability, and 62.0% reported having ≥1 functional limitation.

The relation between diabetes and disability may be due to complications of diabetes, such as neuropathy, peripheral vascular disease, cardiovascular disease, depression, frailty, sarcopenia, and cognitive impairment (77). Stroke and depressive symptoms were especially related to poor functional status in combination with diabetes in older adults in an analysis of Health and Retirement Study 2012–2014 data (78). A study of NHANES 1999–2006 data found that poor glycemic control only explained about 10% of the excess odds of disability associated with diabetes, while the inclusion of comorbidities (namely cardiovascular disease and obesity) accounted for 85% of the excess odds of disability (79).

#### Sensory Dysfunction

Diabetes can cause impairment in somatic, visual, vestibular, and auditory sensory function in older adults (80,81). Peripheral neuropathy (somatosensory dysfunction) is highly prevalent in older adults with diabetes. In an analysis of adults age ≥70 years in the Atherosclerosis Risk in Communities Study (2016–2017), peripheral neuropathy (assessed by monofilament and defined as at least one insensate site on either foot) was present in 42.3% of participants with diabetes duration ≥10 years and in 37.0% of participants with diabetes duration <10 years compared to 31.2% of participants without diabetes (82). Peripheral neuropathy is associated with slower gait speed (83), as well as falls and fractures (84). Vestibular dysfunction is more common in older adults with diabetes (85) and can also increase risk of falls (86). Hearing impairment is more common in older adults with diabetes as well (81) and can negatively impact quality of life (87).

#### Polypharmacy

Polypharmacy is a particularly challenging aspect of caring for older adults with diabetes, since they often require multiple medications to optimally manage their diabetes and associated conditions. Although multiple medications are unavoidable in some individuals to achieve glycemic control and to adequately control cardiovascular risk factors, a focus on appropriate prescribing, interventions to increase regimen adherence, and assessment of financial and functional feasibility are crucial to successful care in this population. In a 2010 study of more than 120,000 adults age ≥65 years in the Kaiser Permanente health system, older adults with diabetes were prescribed on average five medications (88). Polypharmacy continues to rise; an NHANES study found that from 1999–2002 to 2015–2020, the proportion of adults with diabetes taking five or more medications increased from 50.0% to 59.9% of adults age 65–74 years and from 51.1% to 75.4% of adults age ≥75 years (89).

Polypharmacy is dangerous because of individual drug adverse effects, drug-drug interactions, and drug-disease interactions. Older adults with diabetes are more likely to be hospitalized for adverse drug reactions (90) and to suffer adverse drug reactions and mortality related to drug reactions (91) while hospitalized compared to older adults without diabetes. Additionally, polypharmacy of six to seven prescription medications is associated with a 1.28-fold higher risk of falls compared to prescription of zero to one medication in older adults with diabetes, after adjusting for demographic factors, health behaviors, and comorbid conditions (92). The Diabetes in America article Medication Use and Self-Care Practices in Persons With Diabetes (93) provides more information on the use of medications to treat diabetes and associated complications.

### Mortality Rates

The presence of diabetes in older adults is associated with a higher risk of death compared to those without diabetes, but this increased relative risk diminishes with advancing age (94). This risk varies by the age at diagnosis, with an estimated 3–4 years lower life expectancy for each additional decade of diabetes duration (95). When comparing mortality rates by age groups using NHANES I (1971–1975) data followed through 1992–1993, the relative risk of death (in those with diabetes compared to those without) declined with age from 3.6 for those age 25–44 years to 1.5 for those age 65–74 years (96). This pattern associated with age has been found across multiple epidemiologic studies (97,98,99).

Diabetes also increases the risk of cardiovascular mortality. In the Study of Osteoporotic Fractures, the hazard of cardiovascular death was more than twice as high for older women with diabetes compared to those without diabetes (HR 2.16, 95% CI 1.74–2.68) (100). Similarly, a study of nearly 1 million adults in the Veterans Affairs Healthcare System from 2002–2014 found that diabetes was associated with an increased risk of all-cause and cardiovascular mortality among adults ≥65 years (101). Diabetes is additionally associated with increased mortality from many cancers and other noncardiovascular causes of death (102,103).

Diabetes-related mortality rates in older adults have declined over time. In a study of NHIS 1998–2015 data, cardiovascular mortality rates among adults age ≥65 years with diabetes decreased steadily throughout the study period (104). Rates also declined among older adults without diabetes, but at a slower pace. Overall, these differential declines in mortality rates have led to a narrowing gap in cardiovascular mortality between older adults with and without diabetes.

### Quality of Life

As advances in diabetes care may extend life, it is equally important to identify components of diabetes care that improve quality of life in older adults (105). Diabetes is associated with lower quality of life among all adults, including older adults (106). For example, among older Mexican Americans, diabetes was associated with lower physical health-related quality of life, as measured by the Medical Outcomes Study Short Form (SF-36) (107). Complications of diabetes and treatment burden, including macrovascular and microvascular complications and hypoglycemia, are associated with lower quality of life as well among adults with diabetes (108). A greater number of geriatric syndromes and higher depression scores are also associated with worse quality of life in older adults with diabetes (109), and quality of life is affected to similar degrees by geriatric syndromes as by diabetes complications in older adults with diabetes (110).

## Approach to Medical Decision-Making in Older Adults

Making decisions regarding the care of older adults with diabetes requires an individualized approach that emphasizes patient preferences, comorbidities, functional status, life expectancy, and overall health status. Despite the availability of new classes of diabetes medications, the fundamental principles for approaching a personalized treatment plan for older adults remain unchanged. An assessment of patient preferences includes evaluating their general health goals, preferences for treatment, preferences for avoiding complications, feasibility of proposed treatment plans, and if applicable, caregiver concerns or preferences. The risks and benefits of additional medications must also be weighed in each individual, as the harms of polypharmacy may outweigh the benefits of additional medications for some individuals. Life expectancy is an important consideration as well, because the benefits of glycemic control can take years to emerge. Diabetes-specific life expectancy estimators can be a helpful tool to identify limited life expectancy (111). Finally, many glucose-lowering drugs are costly, and a consideration of costs should factor into treatment plans. These components can be used to create an individualized and holistic treatment plan (112).

### Quality-of-Care Standards

Guidelines surrounding the care of older adults with diabetes began evolving based on concepts introduced in care guidelines during the early 2000s. In 2003, the California Healthcare Foundation/American Geriatrics Society panel published guidelines for improving the care of older adults with diabetes that focused on geriatric syndromes and A1C targets based on health status and life expectancy (113). The American Geriatrics Society updated their guidelines in 2013 and added additional content surrounding geriatric syndromes and individualized glycemic goals, as well as stronger recommendations regarding lifestyle modifications for older adults with diabetes (114). In 2011, the European Diabetes Working Party for Older People published guidelines for treating people with diabetes age >70 years (115). These guidelines recommended that treatments be based on the benefit/risk ratio of the intervention for the individual with consideration for hypoglycemia, self-management, cognitive status, and life expectancy. The American Diabetes Association’s 2026 guidelines for older adults emphasize an individualized approach to glycemic goals and treatment of comorbidities based on patient goals, functional status, and other comorbidities, screening for geriatric syndromes, and avoiding hypoglycemia by utilizing new technologies and avoiding medications that worsen the risk of hypoglycemia (116). They suggest an A1C goal of <7.0%–7.5% (<53–58 mmol/mol) for healthy older adults, <8.0% for those with significant limitations or comorbidities, and for older adults with very complex or poor health, no A1C target but rather an avoidance of hypoglycemia and symptomatic hyperglycemia. The Endocrine Society published guidelines in 2019 that also provide a framework to determine glycemic goals based on the individual’s health, functional status, cognitive impairment, and whether medications that may cause hypoglycemia are used (such as insulin or sulfonylureas) (117). Endocrine Society guidelines also suggest regular screening for cognitive impairment/dementia.

A consistent theme of these guidelines is the recommendation to pursue an individualized approach to diabetes care, focusing on clinical and functional heterogeneity and comorbidities and weighing the expected timeframe of benefit of interventions against life expectancy. These guidelines also emphasize screening for geriatric syndromes, and more recent guidelines suggest the use of diabetes technology (such as continuous glucose monitoring [CGM]) to improve diabetes care in older adults.

### Alternative Approaches to Classifying Older Adults With Diabetes by Comorbidity, Frailty, and Function

Given the wide variation among older individuals in pathogenesis and duration of diabetes, as well as comorbidities and complications arising from diabetes, there is a need for practical approaches to classifying older adults with diabetes to understand their individual risk. One such classification system for older adults with diabetes was developed using data from 105,786 adults with diabetes age ≥65 years in the Kaiser Permanente system. The system used 19 comorbidities to classify individuals into three distinct groups and was able to characterize risk of future diabetes complications based on classification (118). A similar schema based on data from the National Social Life, Health, and Aging Project classified older adults with diabetes into three groups based on 11 comorbidities, demographic characteristics, and diabetes-related clinical characteristics. Disability, frailty, and 5-year mortality were significantly associated with classification, potentially supporting an underlying mechanism of secondary frailty and disability (119). Some classification schemes also take into account the underlying pathophysiology of a person’s diabetes by including data on autoantibodies, age at diagnosis, and measurements of pancreatic β-cell function and insulin resistance, although these measures are not commonly collected in clinical practice (18). Comparisons of clusters with genetic information in the latter study gave novel insight into genetic associations with clinical features of diabetes, and the clustering also allowed for predictions of an individual’s risks for diabetes complications. All of these classifications give insight into the factors associated with diabetes outcomes and can help highlight a person’s risks and guide individualized treatment plans for older adults with diabetes.

### Framework for Medical Decision-Making in Older Adults

More sophisticated classification schemes of older adults with diabetes are the first step and can be a formal way to take in account the multiple variables that determine a person’s overall health status and gauge their risks of diabetes complications (18,118,119). The 4S Pathway is an approach to weave together the many considerations that arise when caring for older adults with diabetes. The pathway is a series of four practical algorithms that focus on (1.) seeking diabetes-related triggers of declining health or well-being that may require further investigation (e.g., missed doses of medications, confusion/delirium, falls), (2.) shared decision-making, (3.) setting and resetting goals, and (4.) simpler and safer medications. The goal of the pathway is to provide a formal framework to identify clinical, social, and functional status, elicit patient preferences, and develop personalized treatment plans through shared decision-making (120).

## Preventing Diabetes

In the NHANES 2017–2023, more than half of older adults met criteria for prediabetes (based on A1C 5.7%–<6.5% or fasting plasma glucose 100–<126 mg/dL) (Table 3). Rates of progression may be lower than in younger populations meeting the prediabetes criteria and A1C can increase nonpathologically with age (21), but given the size of the older adult prediabetes population, preventing the progression of diabetes in older adults remains important.

The Diabetes Prevention Program (DPP) is the largest trial that has evaluated the role of lifestyle interventions and metformin in preventing diabetes. The overall study enrolled >3,000 adults with prediabetes (defined by impaired glucose tolerance with elevated fasting glucose in all groups except American Indians), about 20% of whom were age ≥60 years (121). The mean age of adults age ≥60 years in the DPP was 66.4 years and ranged from 60 to 85 years. The study population had good representation among older adults in their mid-sixties but far less participation from adults age ≥70 years. This study found reductions in the incidence of diabetes with the lifestyle intervention and metformin treatment after 2.8 years of follow-up. The reductions with the lifestyle intervention were largest for adults age ≥60 years compared to adults ages 25–44 and 45–59 years (71% vs. 48% and 59%, respectively). Interestingly, adults age ≥60 years did not experience reductions in diabetes incidence with metformin, while younger subjects did. Ten-year (122) and 15-year (123) follow-up data from the DPP provided evidence for the persistent benefits of the lifestyle intervention compared to drug therapy in older adults, as well as secondary benefits of the lifestyle intervention, including reductions in urinary incontinence (124) and improvements in quality of life (125).

## Preventing Complications of Diabetes

### Preventing Cardiovascular and Microvascular Complications

#### Lifestyle Changes

Changes in diet and physical activity patterns are a cornerstone of lowering glucose and preventing complications of diabetes. Substantial evidence exists that weight loss through diet and physical activity (as opposed to through medication or bariatric surgery, which can have additional positive effects on glucose metabolism) can lead to improvements in glycemic control (126). The Look AHEAD (Action for Health in Diabetes) trial compared an intensive lifestyle intervention to diabetes support and education in 5,145 adults age 45–76 years with overweight or obesity with a mean follow-up of almost 10 years. There was no significant difference in cardiovascular morbidity and mortality between the groups, but the lifestyle intervention group had more weight loss, which was sustained through follow-up, greater improvements in fitness, lower A1C levels, lower blood pressure, and less frequent use of antihypertensive medications, statins, and insulin (127). The lifestyle intervention also showed significant benefits on physical functioning (128), sleep apnea (129), and depression (130). After a mean follow-up of 15.6 years, the lifestyle intervention also reduced kidney disease progression in adults age ≥60 years at baseline but did not have an effect on kidney disease progression in younger participants (131). A subgroup analysis of adults age 58.8 years (the median age) and older found that older adults had greater improvements in physical functioning with the intervention compared to younger adults (132). Participants age 65–76 years saw greater weight loss than younger participants and comparable improvements in A1C levels and SBP relative to younger participants (133). However, inclusion criteria for the Look AHEAD trial included the ability to complete a maximum exercise stress test (participants with any abnormality on stress test were excluded, unless evaluated by a cardiologist and deemed safe to participate in the lifestyle intervention). Thus, older adults with frailty or low functional status were likely not included.

#### Glucose Control

Several clinical trials have evaluated the benefits of glucose control in adults with diabetes but have either excluded adults age >65 years or only included older adults without significant functional impairment or comorbid illnesses. These studies were conducted prior to the availability of newer glucose-lowering agents, such as glucagon-like peptide-1 (GLP-1) receptor agonists (RAs), GLP-1/glucose-dependent insulinotropic polypeptide (GIP) RAs, and sodium-glucose cotransporter-2 (SGLT2) inhibitors. Additionally, these trials largely enrolled White adults, and evidence exists that Black adults have higher A1C results compared to White adults for the same mean glucose level (134). Thus, A1C targets may be less generalizable to Black older adults with diabetes.

The United Kingdom Prospective Diabetes Study (UKPDS) showed that glycemic control reduces the risk of microvascular complications; however, the study excluded adults age >65 years and only enrolled subjects with newly diagnosed type 2 diabetes (135,136). During the post-trial follow-up at 10 and 24 years, as participants entered the older age range, the benefits of early glucose lowering on microvascular complications persisted, and benefits for reducing mortality and myocardial infarctions emerged and persisted (137,138).

Following the UKPDS, the Action to Control Cardiovascular Risk in Diabetes (ACCORD) trial enrolled adults with diabetes age 40–79 years (mean age 62 years) and compared intensive glucose control therapy (A1C <6.0% [<42 mmol/mol]) to standard therapy (A1C 7.0%–7.9% [53–63 mmol/mol]) (139). The trial was ended after a mean follow-up of 3.5 years because the intensive therapy group had a higher mortality rate than the standard therapy group (HR 1.22, 95% CI 1.01–1.46). More intensive glycemic control was associated with improved microvascular outcomes (diabetic retinopathy (140) and development of albuminuria and neuropathy (141)). Cardiovascular outcomes were not significantly different between adults age ≥65 years and adults age <65 years (139), but increased age was significantly associated with a higher risk of severe hypoglycemia (142). At 9 years of follow-up, the 3.7 years of intensive glucose control had no significant effect on death or nonfatal cardiovascular events but was associated with reduction in cardiovascular-related death (143).

The Action in Diabetes and Vascular Disease: Preterax and Diamicron MR Controlled Evaluation (ADVANCE) study included participants age ≥55 years (mean age 66 years) with type 2 diabetes and a history of major macrovascular or microvascular disease and at least one vascular risk factor (144). Participants were randomized to intensive glucose control (A1C <6.5%) or standard glucose control. The intensive glucose therapy group had a significant reduction in the incidence of major microvascular events (HR 0.86, 95% CI 0.77–0.97) but no significant difference in the incidence of major macrovascular events (HR 0.94, 95% CI 0.84–1.06). No difference in major macrovascular and microvascular events was observed between participants age <65 years and those age ≥65 years. At 6 years of follow-up (when all participants would be ≥60 years old), there was no evidence that intensive glucose control had any impact on mortality or macrovascular events (145).

In contrast, the Veterans Affairs Diabetes Trial (VADT) showed no benefits from intensive glucose control. The VADT randomized 1,791 veterans (mean age 60.4 years) to intensive glucose control versus standard control (146). The VADT found no significant differences in major cardiovascular events, death, or microvascular events between the two groups after a median follow-up of 5.6 years. In post-hoc analyses, adults with diabetes duration >20 years had an increased risk for cardiovascular events with intensive therapy (147). At 10-year follow-up, the participants who had been part of the intensive glucose control group for 5.6 years had 8.6 fewer major cardiovascular events per 1,000 person-years compared to those who received standard therapy, but there was no difference in overall survival (148).

Since older adults with diabetes were excluded from the UKPDS, data from epidemiologic studies on the relationship between glycemic control and complications are relevant. In adults age ≥50 years with type 2 diabetes from the U.K. General Practice Research Database, both low and high A1C values were associated with increased all-cause mortality and cardiac events (149). In a large retrospective cohort study of 71,092 adults with type 2 diabetes age ≥60 years, the risk of any nonfatal complication rose linearly for A1C >6.0%, but mortality had a U-shaped relationship with A1C. Mortality risk was lowest for A1C levels between 6.0% and 9.0% (75 mmol/mol) (adjusted HR 0.83) and higher for A1C levels ≥11.0% (≥97 mmol/mol) (adjusted HR 1.31) compared to those with A1C <6.0%. Age did not affect this U-shaped relationship between mortality and A1C (150).

It is important to acknowledge that the trials and observational studies of the period before 2010 are based on glycemic control achieved with medications available at the time (e.g., metformin, sulfonylureas, and insulin). In the UKPDS, intensive glycemic control compared to standard management in individuals with newly diagnosed diabetes reduced microvascular complications during the trial, and those benefits persisted after the trial (legacy effect). Intensive glycemic control did not produce consistent cardiovascular benefits during the course of the trials, but there appeared to be some post-trial benefits. The ACCORD trial is distinct among these trials, as it found increased mortality among participants in the intensive glucose control arm. For older adults, the mixed trial findings contributed to the concept that the pursuit of intensive glycemic control is likely to be most beneficial for older adults with longer life expectancy.

##### Glucose-Lowering Medications

Based on a new analysis of NHANES 2017–2020 data conducted for Diabetes in America, metformin (58.5%) and sulfonylureas (30.1%) were the oral agents most commonly used for glucose control among adults age ≥65 years with diabetes (Table 8). Only a small subset of older adults were using the newer GLP-1 RAs (4.0%) and SGLT2 inhibitors (3.7%) during this time period. A substantial proportion of older adults used insulin (27.7%). More information on medication use for diabetes is provided in the Diabetes in America article Medication Use and Self-Care Practices in Persons With Diabetes (93).

###### Metformin

Metformin is widely prescribed for older adults with diabetes given its low cost and low risk of hypoglycemia (151). Vitamin B12 deficiency is associated with metformin use (152), which may be particularly concerning for older adults with diabetes who are already at an increased risk of cognitive impairment and dementia. Metformin should be dose-reduced or stopped in individuals with renal impairment (151), which is a common comorbidity in older adults with diabetes.

###### Insulin

Insulin use can cause hypoglycemia (153) and is associated with an increased risk of falls among older adults with diabetes (28). Insulin can also be challenging to administer for older adults with limited dexterity. However, it may be the only option for adults with insulin-deficient type 2 diabetes and is necessary for the management of type 1 diabetes. Insulin can also be used with individuals who have renal impairment.

###### Sulfonylureas

Sulfonylurea drugs carry a risk of hypoglycemia (154), and the presence of chronic kidney disease is associated with an increased risk of hypoglycemia (155). Sulfonylureas have also been associated with a higher risk of falls and fractures in older adults with diabetes (156,157). However, there may be cases where sulfonylureas remain a good choice for older adults with diabetes due to affordability or intolerance to other medications.

###### Dipeptidyl Peptidase-4 Inhibitors

Dipeptidyl peptidase-4 (DPP-4) inhibitors are associated with a lower risk of hypoglycemia than sulfonylureas or insulin (154,156) and, thus, can be a good glucose-lowering medication for older adults. DPP-4 inhibitor use is associated with similar cardiovascular outcomes to sulfonylurea use among older adults with diabetes (154,156,158).

###### Glucagon-Like-Peptide-1 Receptor Agonists/Glucose-Dependent Insulinotropic Polypeptide Receptor Agonists

In recent years, GLP-1 and GLP-1/GIP RAs have been increasingly recommended for management of type 2 diabetes with high A1C, established or high risk of atherosclerotic cardiovascular disease, chronic kidney disease, or metabolic dysfunction-associated steatotic liver disease (MASLD) (159). These medications not only lower glucose levels but are also associated with protection against many of the comorbidities of diabetes, such as cardiovascular diseases, renal dysfunction, adiposity, and MASLD.

Some trials for GLP-1 RAs stratified outcomes by age, and a meta-analysis analyzed outcomes for older adults of the studies that did stratify. One limitation of these studies is that there were very few participants age ≥75 years in these trials. Across six trials, GLP-1 RAs reduced the risk of major cardiovascular events by 11% (HR 0.89, 95% CI 0.82–0.96) in the overall population. No difference in outcomes was found between adults age ≥65 years and younger participants, although there was evidence that those age ≥75 years had the greatest reduction in cardiovascular events from GLP-1 RAs (160). Additionally, GLP-1 RAs reduced cardiovascular mortality by 22% (HR 0.78, 95% CI 0.63–0.97) and myocardial infarction risk by 15% (HR 0.85, 95% CI 0.73–0.98) with no difference between older and younger participants. Stroke risk was also reduced without differences among age groups. These results are supported by a real-world evidence study that evaluated cardiovascular outcomes of GLP-1 RAs compared to DPP-4 inhibitors in adults age ≥65 years, stratified by a Medicare claims-based frailty index. The study found that frailer adults with the highest risks of adverse cardiovascular outcomes had the greatest reduction in cardiovascular risk (161).

GLP-1 RAs and GLP-1/GIP RAs cause weight loss, including both fat-mass and fat-free mass, which may be undesirable for certain older adults, such as those with dementia, sarcopenia, or malnutrition. Sarcopenia and loss of bone density can occur with any non-exercise-mediated weight loss and, thus, may occur as a side effect of GLP-1 and GLP-1/GIP RAs (162,163). Given that older adults with diabetes are already at higher risk of sarcopenia and osteoporosis, more research is needed to understand and mitigate the effects of GLP-1 and GLP-1/GIP RAs on muscle mass and function in older adults with diabetes. As is the case with many medications, lower doses are often quite effective and better tolerated in older adults; overly rapid weight loss should be avoided, and excessive weight loss may necessitate discontinuation. Most GLP-1 and GLP-1/GIP RAs are injectable, which like insulin, can be challenging for older adults with limited dexterity; this disadvantage may be mitigated by the ability to inject weekly rather than one or more times a day, improving the feasibility of assistance with injections. Finally, although the frailest and highest-risk adults experience the greatest cardiovascular benefit from GLP-1 RAs (161), evidence also suggests that older adults with <4 years of life expectancy may not experience clinically significant benefits from GLP-1 RAs, so an individualized approach is necessary (164).

###### Sodium-Glucose Cotransporter-2 Inhibitors

Similar to GLP-1 and GLP-1/GIP RAs, SGLT2 inhibitors are glucose-lowering medications that also have additional cardiovascular and renal protective effects. Across four randomized controlled trials, a meta-analysis found that SGLT2 inhibitors reduced major adverse cardiovascular events by 10% (HR 0.90, 95% CI 0.83–0.98). There was no difference in outcomes between participants age ≥65 years and participants age <65 years (160). SGLT2 inhibitors also reduced adverse renal outcomes in the overall population (HR 0.61, 95% CI 0.53–0.70) with no differences among age subgroups. Lastly, in adults age ≥65 years, SGLT2 inhibitors reduced the number of hospitalizations for heart failure (HR 0.62, 95% CI 0.51–0.76). There was no effect on heart failure hospitalizations in younger participants, suggesting SGLT2 inhibitors may have greater effectiveness in older individuals. This outcome was also seen in a real-world study of Medicare beneficiaries, where the frailest adults age ≥65 years (with the highest baseline cardiovascular risk) had the greatest cardiovascular benefit from SGLT2 inhibitors (161). A study using Medicare claims data from 2014–2017 also found that an SGLT2 inhibitor reduced cardiovascular and heart failure-related hospitalizations more than a DPP-4 inhibitor (165).

Many adverse effects of SGLT2 inhibitors are theoretical and have not been supported by evidence, but nonetheless should be considered based on individual risk. Older adults with diabetes are at higher risk of infections (43), and SGLT2 inhibitors can increase the risk of genital infections in older adults compared to DPP-4 inhibitors (166). To a lesser extent, SGLT2 inhibitors can also increase the risk of urinary tract infections (167). However, some evidence suggests that older adults have the same rate of genital infections as younger adults on SGLT2 inhibitors (168). Diabetic ketoacidosis (DKA) can also occur in people taking SGLT2 inhibitors, and some data suggest that DKA from SGLT2 inhibitors occurs more frequently in older adults than in younger individuals (166,169). SGLT2 inhibitors can also be volume-depleting, which is a concern for older adults who may be prone to dehydration and orthostasis, although a meta-analysis found no increase in orthostatic hypotension with SGLT2 inhibitor use at any age (170). Volume depletion could also increase the risk of acute kidney injury; however, a Medicare claims study from 2013–2017 found that SGLT2 inhibitors actually had a lower risk of acute kidney injury compared to GLP-1 RAs or DPP-4 inhibitors in older adults with diabetes (171). There may be diminishing benefits of SGLT2 inhibitors in people with <4 years of life-expectancy (164).

#### Blood Pressure Control

Multiple trials have studied the importance of blood pressure control in adults with diabetes. The ADVANCE study randomized participants to a fixed combination of perindopril and indapamide or placebo. Initial blood pressure levels were 145/81 mmHg in both study arms (172). After a mean follow-up of 4.3 years, the intervention arm had a mean reduction in blood pressure of 5.6/2.2 mmHg compared to placebo, a relative risk reduction of major macrovascular or microvascular events of 9% (HR 0.91, 95% CI 0.83–1.00, p=0.04), and a relative risk reduction of death from cardiovascular disease of 18% (HR 0.82, 95% CI 0.68–0.98, p=0.03). At 6 years of follow-up, the reductions in risks of death and cardiovascular death were smaller but still present in the intervention group (145). A subgroup analysis of the INVEST trial (International Verapamil SR-Trandolapril Study), which included adults age ≥50 years with diabetes and coronary artery disease, found that tight SBP control (SBP <130 mmHg) was not associated with improved cardiovascular outcomes compared with usual control (SBP 130–140 mmHg) (173). The ACCORD-BP trial also did not show benefits from lowering to SBP <120 mmHg compared to <140 mmHg for major adverse cardiovascular events (174). However, the ACCORD-BP trial had a lower number of cardiovascular events than had been assumed for power calculations, and the intensive glycemic control may have masked benefits of blood pressure control (175).

More recent research has provided evidence of benefits for intensive blood pressure control, although it was not conducted in the United States and may be less generalizable to adults in the United States. The Blood Pressure Control Target in Diabetes (BPROAD) trial of 12,821 adults age ≥50 years in China found that intensive SBP control to <120 mmHg compared to <140 mmHg was associated with significantly lower incidence of major cardiovascular events, and this effect was present for both adults age <65 years and adults age ≥65 years (176). There was no significant effect of intensive blood pressure control for adults age ≥80 years, but there was a very small number of participants in this age group, which likely affected power. The rate of serious adverse events between groups was not significantly different, although symptomatic hypotension occurred in 0.1% of intensive treatment participants versus <0.1% of control group participants (p=0.05) and hyperkalemia occurred in 2.8% of intensive treatment participants compared to 2.0% of control group participants (p=0.003).

#### Lipid Control

Several studies in middle- and older-aged adults with and without diabetes have established the benefits of statin therapy in older adults with diabetes. In a clinical trial of adults age 70–82 years with a history of or high risk for vascular disease, participants were randomized to pravastatin or placebo and followed for about 3 years. Participants who received pravastatin had a 34% reduction in their LDL cholesterol levels and a 15% decreased risk of cardiovascular disease events (177). Additionally, the Heart Protection Study found that simvastatin therapy was associated with a 31% risk reduction in first major vascular event among adults age 65–80 years with diabetes and without known baseline coronary artery disease (178). A subgroup analysis of the Collaborative Atorvastatin Diabetes Study (CARDS) of adults age 65–75 years showed that atorvastatin use compared to placebo conferred a 38% reduction in relative risk (95% CI -58 to -8) of major cardiovascular events in older adults and a number needed to treat of 21 to avoid one event over 4 years (179).

For older adults with intolerances to statins or suboptimal cholesterol lowering from statins, other lipid-lowering agents include ezetimibe, proprotein convertase subtilisin/kexin type 9 (PCSK9) inhibitors, and bempedoic acid. The Ezetimibe Lipid-Lowering Trial on Prevention of Atherosclerotic Cardiovascular Disease in 75 or Older (EWTOPIA 75) trial randomized 3,796 adults age ≥75 years with no use of a lipid-lowering drug in the preceding month to receive ezetimibe versus usual care. Although the overall trial showed a reduction in major cardiovascular events, a subgroup analysis of participants with diabetes did not show a significant reduction in events (180); however, the overall number of participants with diabetes in the trial was small, and the trial may have been underpowered for diabetes. PCSK9 inhibitors are effective in reducing cardiovascular risk in individuals with diabetes (181) and in adults age ≥75 years (182), but little data exist specifically for older adults with diabetes. A meta-analysis of PCSK9 inhibitor effect on cardiovascular events in adults with diabetes (mean age 60.5 years) found that use of alirocumab or evolocumab significantly reduced the risk of major cardiovascular events (odds ratio [OR] 0.82, 95% CI 0.74–0.90) (181). Data for effects of bempedoic acid in older adults are similarly lacking, but a study of 6,373 adults with diabetes (mean age 66.5 years) showed a reduction in major cardiovascular events with bempedoic acid use compared to placebo (183).

#### Aspirin

Aspirin for primary prevention in people without established cardiovascular disease can reduce the risk of cardiovascular events but also raises the risk of major bleeding in older adults (184,185). In a post-hoc analysis of ACCORD trial data, participants with diabetes (average age 62.8) who used aspirin for primary prevention did not have a significantly different risk of incident cardiovascular disease or all-cause mortality compared to those who did not use aspirin (186). In contrast, the ASCEND (A Study of Cardiovascular Events in Diabetes) trial showed that aspirin use decreased the rate of serious vascular events in adults with diabetes (mean age 63.2 years and 63.8% of participants were age ≥60 years). Serious vascular events occurred in 8.5% of the aspirin group and 9.6% of the placebo group (rate ratio 0.88, 95% CI 0.79–0.97), but major bleeding occurred in 4.1% of the aspirin group compared to 3.2% of the placebo group (rate ratio 1.29, 95% CI 1.09–1.52) (187). American Diabetes Association 2026 guidelines suggest that aspirin may be considered for primary prevention in adults with diabetes age 50–70 years who are at increased cardiovascular risk, but for adults age ≥70 years, the risk of bleeding likely outweighs the cardiovascular benefit (188).

#### Nonpharmacologic Interventions

##### Digital Technology

CGM allows for real-time measurement of interstitial glucose levels without painful finger pricks and has been shown to improve quality of life and reduce hypoglycemia-related emergency department visits in older adults with diabetes (189). A study of 203 older adults with type 1 diabetes found that CGM reduced the amount of time spent in hypoglycemia (defined as glucose levels <70 mg/dL [<3.89 mmol/L]) compared to traditional monitoring over 6 months of follow-up (190). Another randomized controlled trial of 116 older adults with type 1 or type 2 diabetes showed a reduction in A1C and reduced glycemic fluctuations over 24 weeks of follow-up (191). Barriers to CGM use in older adults can include challenges with digital literacy and structural barriers that prevent access to new technologies (192).

Use of insulin administration technology for type 1 diabetes in older adults is growing. A large study of a hybrid closed-loop system, which automatically adjusts basal insulin in response to a CGM, enrolled 649 adults age ≥60 years. These older adults had a time in range (defined as the amount of time spent in the target glucose range of 70–180 mg/dL [3.89–10.00 mmol/L]) of 77% and only 1.9% of blood glucose values were <70 mg/dL compared to 71% time in range and 2.3% of blood glucose values <70 mg/dL for adults using the manual system (193). Smaller studies have also had promising results for hybrid closed-loop insulin delivery systems in older adults: one study found that hybrid system users had increased time in range and reduced time spent in hypoglycemia (194), and another found improved glycemic control, no increased risk of hypoglycemia, and increased time spent in range of glycemic target (195).

Mobile health interventions, such as apps, decision support aids, online educational programs, or telemedicine, also have the potential to improve diabetes care in older adults. A systematic review of 16 randomized controlled trials found that use of diabetes-targeted mobile health interventions by older adults with type 2 diabetes resulted in significant improvements in glucose levels, cholesterol levels, and blood pressure (196). Challenges in uptake of mobile health interventions in elderly individuals with diabetes may be similar to challenges in using CGMs or insulin delivery systems and include financial resources, manual dexterity, vision, cognitive function, and possibly caregiver support.

##### Community-Based and Care Coordination Programs

Community-based programs offer an additional nonpharmacologic way to improve the diabetes care of older adults. Community health workers (CHWs), or individuals with a personal connection to the community they serve, can deliver interventions that have been shown to prevent diabetes-related complications and address disparities (197). A study with Latino adults age ≥55 years found that a CHW-led intervention resulted in greater self-efficacy and improved A1C levels (198). The DPP can also be effectively delivered in community settings to older adults (199), and many Area Agencies on Aging (state-sponsored agencies that coordinate services for older adults) offer or partner with community organizations to offer diabetes management programs (200). Care coordination programs, which can include individualized planning, needs assessments, and regular communication/monitoring, have also had positive outcomes among older adults with diabetes (201).

### Preventing Geriatric Syndromes

While several studies have examined strategies to prevent macrovascular and microvascular complications of diabetes, fewer studies have addressed the prevention of geriatric syndromes in older adults with diabetes.

#### Dementia

Dementia or cognitive impairment is a sentinel condition for diabetes because it affects background mortality and changes the extent to which individuals are able to care for themselves. While dementia poses a significant challenge to self-management, evidence for how to prevent dementia is scant. A major study on diabetes and dementia, the ACCORD-MIND trial, found no benefits from intensive glucose control or blood pressure control on improving cognitive outcomes compared to standard therapy (202), which was sustained at 4-year follow-up (203). However, there is evidence from observational studies that GLP-1 RAs (204,205) and SGLT2 inhibitors (206) can reduce the risk of dementia in older adults with diabetes, although clinical trial evidence is still needed. Given the association of severe, recurrent hypoglycemia with development of dementia (52), avoidance of hypoglycemia is critical for preventing dementia. A high index of suspicion for cognitive impairment should be present when evaluating older adults with diabetes. Worsening cognitive function should be suspected in older adults who develop nonadherence, frequent hypoglycemia, or sudden deterioration of glycemic control. Screening for cognitive dysfunction is recommended for all older adults with diabetes (116), using clinical tools such as the Mini-Cog (207), Mini-Mental State Examination (208), or Montreal Cognitive Assessment (209).

#### Falls

The increased risk of falls in older adults with diabetes is attributable to a combination of factors, such as frailty/sarcopenia, gait/balance abnormalities, loss of vision and/or hearing, and osteoarthritis, along with the diabetes-related complications of neuropathy, retinopathy, polypharmacy, and hypoglycemia (92). While good glycemic control prevents progression of neuropathy and retinopathy, the trade-off of polypharmacy or hypoglycemia may increase the risk of falls. Since prevention of complications occurs over decades, the short-term risk of diabetes therapies may outweigh the benefit with advancing age, frailty, and comorbidities. Multiple expert societies recommend regular screening for falls in older adults, and in those who screen positive, gait and balance assessments are recommended, as well as a multifactorial fall risk assessment (210,211). Functional and balance-focused exercise programs have proven effective in preventing falls in older adults (212,213), and it is also important to address other contributors to falls, such as medications, home environment, and footwear (211).

#### Depression

Depression has a significant impact on the mortality and quality of life in older adults with diabetes (66,214). Because of the high prevalence of depression in older adults with diabetes (63) and the great burden of depression (110), older adults with diabetes should be routinely screened for depression (116). Since depression can present atypically in older adults, using geriatric-specific screening tools, like the Geriatric Depression Scale, may enhance screening and allow earlier identification and subsequent treatment of depression (215).

#### Polypharmacy

The older adult diabetes population is at high risk for polypharmacy and has increased susceptibility to the side effects of medications, which can lead to adverse health outcomes (37,216). However, comprehensive diabetes care sometimes necessitates multiple medications to appropriately manage diabetes and its complications in accordance with published guidelines (120). Thus, the trade-offs between the potential benefits and risks of adding new diabetes-related and other medications for older adults with diabetes should be carefully weighed. Deprescribing is also a key part of addressing polypharmacy and requires regular evaluation of patient medication lists to screen for potentially inappropriate medications (217). The Beers Criteria lists medications that are potentially inappropriate for older adults and can be used to guide decisions on prescribing and deprescribing (218). Sulfonylureas and insulin regimens employing only short-acting insulin (“sliding scale insulin”) are on the Beers Criteria. The STOPP/START (Screening Tool of Older Persons’ Prescriptions and Screening Tool to Alert to Right Treatment) criteria can also be used to identify potentially inappropriate medications and potential prescribing omissions to address polypharmacy in older adults (219).

### Hypoglycemia

Avoidance of hypoglycemia should be an important consideration when choosing therapeutic agents, establishing glycemic goals, and deprescribing medications in older adults. Older frail adults are at high risk for severe sequelae of hypoglycemia, even if the hypoglycemia is mild (1,220,221). The early adrenergic manifestations (tremors, sweating) of hypoglycemia may become blunted with age, and thus, older adults may not experience symptoms of hypoglycemia until their blood sugar is low enough to cause neuroglycopenic symptoms (dizziness, weakness, delirium, confusion) (222). Hypoglycemia unawareness may be more prevalent in older adults, with recognition of symptoms of hypoglycemia at lower blood sugar levels than younger adults (1).

Despite the clinical importance of hypoglycemia in older adults, several studies suggest that many older adults receive intensive glucose-lowering treatments that increase the risk of hypoglycemia. A study of Medicare claims revealed that the risk of hospitalization due to acute hyperglycemia declined, but the risk of hospitalization due to hypoglycemia increased by 11.7% (from 94 to 105 admissions per 100,000 person-years) between 1999 and 2011 (223). These findings suggest that treatments may have become overly aggressive over time. Data from the NHIS 2007–2011 and the National Electronic Injury Surveillance System-Cooperative Adverse Drug Event Surveillance found that nearly 100,000 emergency department visits for insulin-related hypoglycemia and errors occurred annually and that adults age ≥80 years were over twice as likely to have an insulin-related hypoglycemia emergency encounter than adults age 65–79 years (224). Older adults on insulin monotherapy were over three times as likely to have an emergency encounter than older adults on insulin plus oral diabetes medications. However, data from healthcare utilization likely severely underestimate the true incidence of hypoglycemic events as people do not always present for care; one study estimated that only 5% of hypoglycemia events are captured by healthcare surveillance data (225).

Despite the lack of clinical trial data in support of intensive treatment and despite care guidelines recommending less-intensive goals, it has been repeatedly found that even very old adults with diabetes continue to receive intensive glucose-lowering treatments, irrespective of health status. In a cross-sectional study from 2014–2016 of 42,669 adults with diabetes age ≥75 years, one-quarter had tightly controlled diabetes (A1C <7%) with medications that have a high risk of hypoglycemia (226). A study that analyzed Medicare claims from 2007–2017 found that of people taking insulin and/or a sulfonylurea who had an emergency visit or hospitalization for hypoglycemia, fewer than 50% had deintensification of their insulin or sulfonylurea within 100 days after the hospital encounter (153).

The use of newer diabetes medication with lower risks of hypoglycemia and use of new technology, such as CGM, are strategies to reduce hypoglycemia in older adults. Additionally, deprescribing interventions can reduce hypoglycemia risk. Hypoglycemia risk stratification tools based on patient data from the electronic medical record can screen and identify individuals at high risk of hypoglycemia who would benefit from targeted deprescribing interventions (227). Education initiatives for patients and prescribers (228) and pharmacist-led medication reviews (229,230,231) can also facilitate deprescribing of inappropriate medications to prevent hypoglycemia. Finally, Diabetes Self-Management Education and Support (DSMES) programs are covered by Medicare and can help older adults build skills to manage their diabetes and prevent hypoglycemia.

## Economic Consequences of Diabetes

### Medicare

In the United States, the vast majority of adults age ≥65 years have access to health insurance through the Medicare program. The Diabetes in America article Health Insurance and Diabetes contains additional information about insurance coverage of individuals living with diabetes (232). Medicare was established by the federal government in 1965 and has two major components: (1.) the hospital benefit under Part A and (2.) outpatient medical services under Part B. Beneficiaries have the option of an open-network single payer healthcare plan (traditional Medicare) or a network plan (Medicare Advantage or Medicare Part C) where the federal government pays for private health coverage that includes hospital benefits and outpatient medical services. Medicare Part D is an outpatient prescription drug plan available to beneficiaries with both traditional Medicare and Medicare Advantage. The Social Security Amendments of 1972 extended Medicare coverage to individuals with end-stage renal disease in order to provide coverage for outpatient dialysis. In 1997, the Balanced Budget Act provided coverage for blood glucose monitors and testing strips, in addition to outpatient diabetes self-management training (233). Medicare began covering CGM in 2017 (234) and the DPP in 2018 (235), if certain conditions were met.

### Costs of Diabetes

The total national direct and indirect cost of diabetes in the United States was estimated to be $412.9 billion in 2022 based on national public and private data sources (236). An estimated $205 billion of healthcare expenditures attributable to diabetes were for adults age ≥65 years. The largest contributors to these direct medical costs were hospital inpatient stays ($68 billion), prescription medications (excluding glucose-lowering medications) ($64 billion), physician office visits ($26 billion), noninsulin glucose-lowering medications ($12 billion), and insulin ($10 billion). The average cost per person per year with diabetes was estimated to be $7,482 and $17,180 for individuals ages <65 and ≥65 years, respectively. The share of diabetes-related healthcare expenditures attributable to adults age ≥65 years grew from 61% to 67% between 2017 and 2022, reflecting the growing population of older adults.

The direct nonmedical costs of diabetes care in older adults are also substantial. A nationally representative survey in 2002 of adults age ≥70 years found that older adults with diabetes required an average of 10.5–14.4 hours of informal caregiving per week compared to only 6.1 hours per week for those without diabetes (p<0.01) (237).

### Growth in Spending Over Time

The cost of diabetes care has risen dramatically over time. Estimates indicate that total direct medical costs for all individuals with diabetes increased by 35% from 2012 to 2022. However, this growth may be slowing: costs only rose by 7% between 2017 and 2022 (236). Costs specifically for older adults are likely to continue growing as the U.S. population continues to age (238). Increased use of the expensive new GLP-1 and GLP-1/GIP RAs and SGLT2 inhibitors is also likely to drive costs in the coming years. Although these medications have substantial medical benefit, their current prices prevent them from being cost-effective (239,240,241).

### Efforts to Improve Care and Curb Spending

Nearly all of the care of older adults with diabetes in the United States is covered by Medicare, and thus Medicare policy changes can have a substantial impact on the provision of care to older adults with diabetes. The Medicare Shared Savings Program established accountable care organizations (ACOs) in 2012 as a potential solution to improve care and decrease costs (242). Medicare ACOs have diabetes quality care measures as part of their contract with Medicare to measure and incentivize high-quality diabetes care (243). Research has shown that the ACO model largely produced overall healthcare savings (244,245,246,247) and can improve quality of diabetes care (243).

Patient-centered medical homes are another model to improve patient care and reduce spending. The CMS developed the Multi-Payer Advanced Primary Care Practice Demonstration, through which Medicare offered additional payments to provider groups that became patient-centered medical homes starting in 2011 (248). Literature suggests that patient-centered medical homes can improve the quality of diabetes care (249,250,251) and reduce costs (249).

#### The Inflation Reduction Act

In 2022, the Inflation Reduction Act was established, allowing the federal government to negotiate the prices Medicare pays for certain drugs with manufacturers (252). Several diabetes medications (two SGLT2 inhibitors, a DPP-4 inhibitor, and several insulin formulations) were among the first medications for which the prices paid by Medicare were negotiated (253). The Inflation Reduction Act also included a cap on out-of-pocket costs for insulin, and an early analysis suggests that the passage of the Act was associated with an increase in the total number of insulin fills by Medicare beneficiaries (254).

## Conclusion

The number of older adults with diabetes is growing as the American population ages, and older adults with diabetes are clinically and demographically heterogeneous. This heterogeneity necessitates tailored treatment plans from approaches that classify older adults based on comorbidities, complications, and life expectancy. Geriatric syndromes are a burden in older adults with diabetes, and comprehensive diabetes care should address these syndromes. New glucose-lowering medications that also protect against diabetes-related comorbidities have revolutionized diabetes care, but more data are needed about their use in older adults. Novel diabetes technologies can also help manage glucose levels and prevent hypoglycemia. The costs of diabetes care for older adults continue to grow. Innovative approaches to preventing and managing diabetes in older adults are needed to individualize treatment, ensure comprehensive and quality care, leverage new technologies and drugs, and control rising costs.

## List of Abbreviations

A1C: glycated hemoglobin
ACCORD: Action to Control Cardiovascular Risk in Diabetes
ACO: accountable care organization
ADVANCE: Action in Diabetes and Vascular Disease: Preterax and Diamicron MR Controlled Evaluation
BMI: body mass index
CGM: continuous glucose monitoring
CHW: community health worker
CI: confidence interval
CMS: Centers for Medicare and Medicaid Services
DKA: diabetic ketoacidosis
DPP: Diabetes Prevention Program
DPP-4: dipeptidyl peptidase-4
GIP RA: glucose-dependent insulinotropic polypeptide receptor agonist
GLP-1 RA: glucagon-like peptide-1 receptor agonist
HR: hazard ratio
LDL: low-density lipoprotein
Look AHEAD: Action for Health in Diabetes
MASLD: metabolic dysfunction-associated steatotic liver disease
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
NPALS: National Post-acute and Long-term Care Study
PAD: peripheral artery disease
PCSK9: proprotein convertase subtilisin/kexin type 9
SBP: systolic blood pressure
SGLT2: sodium-glucose cotransporter-2
UKPDS: United Kingdom Prospective Diabetes Study
VADT: Veterans Affairs Diabetes Trial

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Albumin-to-creatinine ratio: mg/g x 0.113 = mg/mmol

Cholesterol: mg/dL x 0.0259 = mmol/L

Glucose: mg/dL x 0.0555 = mmol/L

## Funding

Dr. Mitchell is supported by a Health Resources and Services Administration training grant (T32 HP42019). Dr. Huisingh-Scheetz is supported by P50MD017349, R01AG043538, 1R61AG086824, and R01AG048511. Dr. Huang is supported by P50MD017349, K24AG069080, P30DK092949, R01AG060756, and R01AG048511.

## Acknowledgment

This is an update of Laiteerapong N, Huang ES. Diabetes in Older Adults. Chapter 16 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 16.1–16.26.

## Article History

Received in final form on March 10, 2026.

## References

1 Bellary S, Kyrou I, Brown JE, Bailey CJ. Type 2 diabetes mellitus in older adults: clinical considerations and management. Nat Rev Endocrinol. 2021;17(9):534-548. doi:10.1038/s41574-021-00512-2 34172940
2 Chia CW, Egan JM, Ferrucci L. Age-related changes in glucose metabolism, hyperglycemia, and cardiovascular risk. Circ Res. 2018;123(7):886-904. doi:10.1161/CIRCRESAHA.118.312806 30355075
3 Karakelides H, Irving BA, Short KR, O’Brien P, Nair KS. Age, obesity, and sex effects on insulin sensitivity and skeletal muscle mitochondrial function. Diabetes. 2010;59(1):89-97. doi:10.2337/db09-0591 19833885
4 Amati F, Dubé JJ, Coen PM, Stefanovic-Racic M, Toledo FGS, Goodpaster BH. Physical inactivity and obesity underlie the insulin resistance of aging. Diabetes Care. 2009;32(8):1547-1549. doi:10.2337/dc09-0267 19401446
5 Shou J, Chen P-J, Xiao W-H. Mechanism of increased risk of insulin resistance in aging skeletal muscle. Diabetol Metab Syndr. 2020;12:14. doi:10.1186/s13098-020-0523-x 32082422
6 Lee PG, Halter JB. The pathophysiology of hyperglycemia in older adults: clinical considerations. Diabetes Care. 2017;40(4):444-452. doi:10.2337/dc16-1732 28325795
7 Li N, Liu F, Yang P, et al. Aging and stress induced β cell senescence and its implication in diabetes development. Aging (Albany NY). 2019;11(21):9947-9959. doi:10.18632/aging.102432 31721726
8 Martyniak K, Masternak MM. Changes in adipose tissue cellular composition during obesity and aging as a cause of metabolic dysregulation. Exp Gerontol. 2017;94:59-63. doi:10.1016/j.exger.2016.12.007 27939445
9 Tomic D, Harding JL, Jenkins AJ, Shaw JE, Magliano DJ. The epidemiology of type 1 diabetes mellitus in older adults. Nat Rev Endocrinol. 2025;21(2):92-104. doi:10.1038/s41574-024-01046-z 39448829
10 Quattrin T, Mastrandrea LD, Walker LSK. Type 1 diabetes. Lancet. 2023;401(10394):2149-2162. doi:10.1016/S0140-6736(23)00223-4 37030316
11 Inouye SK, Studenski S, Tinetti ME, Kuchel GA. Geriatric syndromes: clinical, research, and policy implications of a core geriatric concept. J Am Geriatr Soc. 2007;55(5):780-791. doi:10.1111/j.1532-5415.2007.01156.x 17493201
12 Laiteerapong N, Huang ES. Diabetes in older adults. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018; 16.1-16.26. https://www.ncbi.nlm.nih.gov/books/NBK567980/
13 Yang K, Yang X, Jin C, et al. Global burden of type 1 diabetes in adults aged 65 years and older, 1990–2019: population based study. BMJ. 2024;385:e078432. doi:10.1136/bmj-2023-078432 38866425
14 Fang M, Wang D, Selvin E. Prevalence of type 1 diabetes among US children and adults by age, sex, race, and ethnicity. JAMA. 2024;331(16):1411-1413. doi:10.1001/jama.2024.2103 38573653
15 Rogers MAM, Kim C, Banerjee T, Lee JM. Fluctuations in the incidence of type 1 diabetes in the United States from 2001 to 2015: a longitudinal study. BMC Med. 2017;15(1):199. doi:10.1186/s12916-017-0958-6 29115947
16 Ng E, Vanderloo SE, Geiss L, Johnson JA. Concordance between self-report and a survey-based algorithm for classification of type 1 and type 2 diabetes using the 2011 population-based Survey on Living with Chronic Diseases in Canada (SLCDC)-Diabetes component. Can J Diabetes. 2013;37(4):249-253. doi:10.1016/j.jcjd.2013.05.007 24070889
17 Davis AK, DuBose SN, Haller MJ, et al. Prevalence of detectable C-peptide according to age at diagnosis and duration of type 1 diabetes. Diabetes Care. 2015;38(3):476-481. doi:10.2337/dc14-1952 25519448
18 Ahlqvist E, Storm P, Käräjämäki A, et al. Novel subgroups of adult-onset diabetes and their association with outcomes: a data-driven cluster analysis of six variables. Lancet Diabetes Endocrinol. 2018;6(5):361-369. doi:10.1016/S2213-8587(18)30051-2 29503172
19 United States Census Bureau. U.S. Older Population Grew From 2010 to 2020 at Fastest Rate Since 1880 to 1890. 2023. Updated May 25, 2023. Accessed March 8, 2025. https://www.census.gov/library/stories/2023/05/2020-census-united-states-older-population-grew.html
20 Pani LN, Korenda L, Meigs JB, et al. Effect of aging on A1C levels in individuals without diabetes: evidence from the Framingham Offspring Study and the National Health and Nutrition Examination Survey 2001–2004. Diabetes Care. 2008;31(10):1991-1996. doi:10.2337/dc08-0577 18628569
21 Rooney MR, Rawlings AM, Pankow JS, et al. Risk of progression to diabetes among older adults with prediabetes. JAMA Intern Med. 2021;181(4):511-519. doi:10.1001/jamainternmed.2020.8774 33555311
22 Arias E, Xu J, Kochanek K. United States life tables, 2023. Natl Vital Stat Rep. 2025;74(6):1-63. doi:10.15620/cdc/174591 40570233
23 Idrees T, Castro-Revoredo IA, Migdal AL, Moreno EM, Umpierrez GE. Update on the management of diabetes in long-term care facilities. BMJ Open Diabetes Res Care. 2022;10(4):e002705. doi:10.1136/bmjdrc-2021-002705 35858714
24 Munshi MN, Florez H, Huang ES, et al. Management of Diabetes in Long-Term Care and Skilled Nursing Facilities: a Position Statement of the American Diabetes Association. Diabetes Care. 2016;39(2):308-318. doi:10.2337/dc15-2512 26798150
25 Lendon JP, Caffrey C, Melekin A, Singh P, Lu Z, Sengupta M. Overview of post-acute and long-term care providers and services users in the United States, 2020. Natl Health Stat Report. 2024;(208). doi:10.15620/cdc/158328 39471284
26 Harris-Kojetin L, Sengupta M, Park-Lee E, et al. Long-term care providers and services users in the United States. Data from the National Study of Long-Term Care Providers, 2013–2014. Vital Health Stat 3. 2016;3(38):x-xii; 1-105. https://www.cdc.gov/nchs/data/series/sr_03/sr03_43-508.pdf 27023287
27 Yadav R, Jain N, Raizada N, Jhamb R, Rohatgi J, Madhu SV. Prevalence of diabetes related vascular complications in subjects with normal glucose tolerance, prediabetes, newly detected diabetes and known diabetes. Diabetes Metab Syndr. 2021;15(5):102226. doi:10.1016/j.dsx.2021.102226 34303917
28 Freire LB, Brasil-Neto JP, da Silva ML, et al. Risk factors for falls in older adults with diabetes mellitus: systematic review and meta-analysis. BMC Geriatr. 2024;24(1):201. doi:10.1186/s12877-024-04668-0 38413865
29 Ali D, Tencerova M, Figeac F, Kassem M, Jafari A. The pathophysiology of osteoporosis in obesity and type 2 diabetes in aging women and men: the mechanisms and roles of increased bone marrow adiposity. Front Endocrinol (Lausanne). 2022;13:981487. doi:10.3389/fendo.2022.981487 36187112
30 Batmani S, Jalali R, Mohammadi M, Bokaee S. Prevalence and factors related to urinary incontinence in older adults women worldwide: a comprehensive systematic review and meta-analysis of observational studies. BMC Geriatr. 2021;21(1):212. doi:10.1186/s12877-021-02135-8 33781236
31 Baker TA, Clay OJ, Johnson-Lawrence V, et al. Association of multiple chronic conditions and pain among older Black and White adults with diabetes mellitus. BMC Geriatr. 2017;17(1):255. doi:10.1186/s12877-017-0652-8 29084525
32 Petrak F, Baumeister H, Skinner TC, Brown A, Holt RIG. Depression and diabetes: treatment and health-care delivery. Lancet Diabetes Endocrinol. 2015;3(6):472-485. doi:10.1016/S2213-8587(15)00045-5 25995125
33 Dove A, Shang Y, Xu W, et al. The impact of diabetes on cognitive impairment and its progression to dementia. Alzheimers Dement. 2021;17(11):1769-1778. doi:10.1002/alz.12482 34636485
34 Dai S, Shu D, Meng F, et al. Higher risk of sarcopenia in older adults with type 2 diabetes: NHANES 1999–2018. Obes Facts. 2023;16(3):237-248. doi:10.1159/000530241 37011596
35 Chen L-K, Chen Y-M, Lin M-H, Peng L-N, Hwang S-J. Care of elderly patients with diabetes mellitus: a focus on frailty. Ageing Res Rev. 2010;9(Suppl 1):S18-S22. doi:10.1016/j.arr.2010.08.008 20849981
36 Kalyani RR, Rodriguez DC, Yeh H-C, Golden SH, Thorpe RJ, Jr. Diabetes, race, and functional limitations in older U.S. men and women. Diabetes Res Clin Pract. 2015;108(3):390-397. doi:10.1016/j.diabres.2015.04.003 25913058
37 Remelli F, Ceresini MG, Trevisan C, Noale M, Volpato S. Prevalence and impact of polypharmacy in older patients with type 2 diabetes. Aging Clin Exp Res. 2022;34(9):1969-1983. doi:10.1007/s40520-022-02165-1 35723858
38 Rothberg AE, Ard JD, Gudzune KA, Herman WH. Obesity management for the treatment of type 2 diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2024. https://www.ncbi.nlm.nih.gov/books/NBK603314/
39 Jia G, Sowers JR. Hypertension in diabetes: an update of basic mechanisms and clinical disease. Hypertension. 2021;78(5):1197-1205. doi:10.1161/HYPERTENSIONAHA.121.17981 34601960
40 Holt RIG, Cockram CS, Ma RCW, Luk AOY. Diabetes and infection: review of the epidemiology, mechanisms and principles of treatment. Diabetologia. 2024;67(7):1168-1180. doi:10.1007/s00125-024-06102-x 38374451
41 Lipska KJ, Gilliam LK, Lee C, et al. Risk of infection in older adults with type 2 diabetes with relaxed glycemic control. Diabetes Care. 2024;47(12):2258-2265. doi:10.2337/dc24-1612 39436715
42 Gavazzi G, Krause K-H. Ageing and infection. Lancet Infect Dis. 2002;2(11):659-666. doi:10.1016/s1473-3099(02)00437-1 12409046
43 Harding JL, Benoit SR, Gregg EW, Pavkov ME, Perreault L. Trends in rates of infections requiring hospitalization among adults with versus without diabetes in the U.S., 2000–2015. Diabetes Care. 2020;43(1):106-116. doi:10.2337/dc19-0653 31615853
44 Kalyani RR, Everett BM, Perreault L, Michos ED. Heart disease and diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2023. https://www.ncbi.nlm.nih.gov/books/NBK597416/
45 Chen C, Ye W, Becker C, Kuo S, Morgenstern LB, Lisabeth LD. Stroke and diabetes in adults. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2025. https://www.ncbi.nlm.nih.gov/books/NBK619717/
46 Qaseem Y, Samra S, German O, Gray E, Gill MK. Self-reported awareness of retinopathy severity in diabetic patients. Clin Ophthalmol. 2020;14:2855-2863. doi:10.2147/OPTH.S267993 33061270
47 Pavkov ME, Koyama AK, Bjornstad P, Nelson RG. Kidney disease and diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2024. https://www.ncbi.nlm.nih.gov/books/NBK609462/
48 Fowler XP, Eid MA, Barnes JA, et al. Trends of concomitant diabetes and peripheral artery disease and lower extremity amputation in US Medicare patients, 2007 to 2019. Circ Cardiovasc Qual Outcomes. 2023;16(6):e009531. doi:10.1161/CIRCOUTCOMES.122.009531 37339191
49 Biessels GJ, Despa F. Cognitive decline and dementia in diabetes mellitus: mechanisms and clinical implications. Nat Rev Endocrinol. 2018;14(10):591-604. doi:10.1038/s41574-018-0048-7 30022099
50 Ding X, Yin L, Zhang L, et al. Diabetes accelerates Alzheimer’s disease progression in the first year post mild cognitive impairment diagnosis. Alzheimers Dement. 2024;20(7):4583-4593. doi:10.1002/alz.13882 38865281
51 Punthakee Z, Miller ME, Launer LJ, et al. Poor cognitive function and risk of severe hypoglycemia in type 2 diabetes: post hoc epidemiologic analysis of the ACCORD trial. Diabetes Care. 2012;35(4):787-793. doi:10.2337/dc11-1855 22374637
52 Srikanth V, Sinclair AJ, Hill-Briggs F, Moran C, Biessels GJ. Type 2 diabetes and cognitive dysfunction—towards effective management of both comorbidities. Lancet Diabetes Endocrinol. 2020;8(6):535-545. doi:10.1016/S2213-8587(20)30118-2 32445740
53 Gregg EW, Yaffe K, Cauley JA, et al. Is diabetes associated with cognitive impairment and cognitive decline among older women? Study of Osteoporotic Fractures Research Group. Arch Intern Med. 2000;160(2):174-180. doi:10.1001/archinte.160.2.174 10647755
54 Casagrande SS, Lee C, Stoeckel LE, Menke A, Cowie CC. Cognitive function among older adults with diabetes and prediabetes, NHANES 2011–2014. Diabetes Res Clin Pract. 2021;178:108939. doi:10.1016/j.diabres.2021.108939 34229005
55 Yau RK, Strotmeyer ES, Resnick HE, et al. Diabetes and risk of hospitalized fall injury among older adults. Diabetes Care. 2013;36(12):3985-3991. doi:10.2337/dc13-0429 24130352
56 Schwartz AV, Sellmeyer DE, Ensrud KE, et al. Older women with diabetes have an increased risk of fracture: a prospective study. J Clin Endocrinol Metab. 2001;86(1):32-38. doi:10.1210/jcem.86.1.7139 11231974
57 Lee RH, Sloane R, Pieper C, et al. Clinical fractures among older men with diabetes are mediated by diabetic complications. J Clin Endocrinol Metab. 2018;103(1):281-287. doi:10.1210/jc.2017-01593 29099931
58 Sudore RL, Karter AJ, Huang ES, et al. Symptom burden of adults with type 2 diabetes across the disease course: Diabetes & Aging Study. J Gen Intern Med. 2012;27(12):1674-1681. doi:10.1007/s11606-012-2132-3 22854982
59 Rosenberger DC, Blechschmidt V, Timmerman H, Wolff A, Treede R-D. Challenges of neuropathic pain: focus on diabetic neuropathy. J Neural Transm (Vienna). 2020;127(4):589-624. doi:10.1007/s00702-020-02145-7 32036431
60 Jiang X, Yuan Y, Ma Y, et al. Pain management in people with diabetes-related chronic limb-threatening ischemia. J Diabetes Res. 2021;2021(1):6699292. doi:10.1155/2021/6699292 34046505
61 Vaishya R, Misra A, Patralekh MK, Kalra P, Vaish A, Migliorini F. Association of type 2 diabetes and osteoarthritis: an umbrella review of systematic reviews and meta-analyses. Eur J Orthop Surg Traumatol. 2025;35(1):111. doi:10.1007/s00590-025-04231-6 40072698
62 Roy T, Lloyd CE. Epidemiology of depression and diabetes: a systematic review. J Affect Disord. 2012;142(Suppl):S8-S21. doi:10.1016/S0165-0327(12)70004-6 23062861
63 Maraldi C, Volpato S, Penninx BW, et al. Diabetes mellitus, glycemic control, and incident depressive symptoms among 70- to 79-year-old persons: the Health, Aging, and Body Composition Study. Arch Intern Med. 2007;167(11):1137-1144. doi:10.1001/archinte.167.11.1137 17563021
64 Byers AL, Vittinghoff E, Lui LY, et al. Twenty-year depressive trajectories among older women. Arch Gen Psychiatry. 2012;69(10):1073-1079. doi:10.1001/archgenpsychiatry.2012.43 23026957
65 Fisher L, Skaff MM, Mullan JT, Arean P, Glasgow R, Masharani U. A longitudinal study of affective and anxiety disorders, depressive affect and diabetes distress in adults with type 2 diabetes. Diabet Med. 2008;25(9):1096-1101. doi:10.1111/j.1464-5491.2008.02533.x 19183314
66 Novak M, Mucsi I, Rhee CM, et al. Increased risk of incident chronic kidney disease, cardiovascular disease, and mortality in patients with diabetes with comorbid depression. Diabetes Care. 2016;39(11):1940-1947. doi:10.2337/dc16-0048 27311494
67 Jaser SS, Roddy MK, Beam AB. Psychosocial and behavioral health among youth and adults with diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2025. https://www.ncbi.nlm.nih.gov/books/NBK612770/
68 Fried LP, Tangen CM, Walston J, et al. Frailty in older adults: evidence for a phenotype. J Gerontol A Biol Sci Med Sci. 2001;56(3):M146-M156. doi:10.1093/gerona/56.3.m146 11253156
69 Mesinovic J, Zengin A, De Courten B, Ebeling PR, Scott D. Sarcopenia and type 2 diabetes mellitus: a bidirectional relationship. Diabetes Metab Syndr Obes. 2019;12:1057-1072. doi:10.2147/DMSO.S186600 31372016
70 Blaum CS, Xue QL, Michelon E, Semba RD, Fried LP. The association between obesity and the frailty syndrome in older women: the Women’s Health and Aging Studies. J Am Geriatr Soc. 2005;53(6):927-934. doi:10.1111/j.1532-5415.2005.53300.x 15935013
71 Ferri-Guerra J, Aparicio-Ugarriza R, Salguero D, et al. The association of frailty with hospitalizations and mortality among community dwelling older adults with diabetes. J Frailty Aging. 2020;9(2):94-100. doi:10.14283/jfa.2019.31 32259183
72 Park SW, Goodpaster BH, Strotmeyer ES, et al. Accelerated loss of skeletal muscle strength in older adults with type 2 diabetes: the Health, Aging, and Body Composition Study. Diabetes Care. 2007;30(6):1507-1512. doi:10.2337/dc06-2537 17363749
73 Pilla SJ, Rooney MR, McCoy RG. Disability and diabetes in adults. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2024. https://www.ncbi.nlm.nih.gov/books/NBK609951/
74 Godino JG, Appel LJ, Gross AL, et al. Diabetes, hyperglycemia, and the burden of functional disability among older adults in a community-based study. J Diabetes. 2017;9(1):76-84. doi:10.1111/1753-0407.12386 26847713
75 Chiu CJ, Wray LA. Physical disability trajectories in older Americans with and without diabetes: the role of age, gender, race or ethnicity, and education. Gerontologist. 2011;51(1):51-63. doi:10.1093/geront/gnq069 20713455
76 Bardenheier BH, Lin J, Zhuo X, et al. Disability-free life-years lost among adults aged ≥50 years with and without diabetes. Diabetes Care. 2016;39(7):1222-1229. doi:10.2337/dc15-1095 26721810
77 de Rekeneire N, Volpato S. Physical function and disability in older adults with diabetes. Clin Geriatr Med. 2015;31(1):51-65, viii. doi:10.1016/j.cger.2014.08.018
78 Quiñones AR, Markwardt S, Botoseneanu A. Diabetes-multimorbidity combinations and disability among middle-aged and older adults. J Gen Intern Med. 2019;34(6):944-951. doi:10.1007/s11606-019-04896-w 30815788
79 Kalyani RR, Saudek CD, Brancati FL, Selvin E. Association of diabetes, comorbidities, and A1C with functional disability in older adults: results from the National Health and Nutrition Examination Survey (NHANES), 1999–2006. Diabetes Care. 2010;33(5):1055-1060. doi:10.2337/dc09-1597 20185736
80 Hewston P, Deshpande N. Falls and balance impairments in older adults with type 2 diabetes: thinking beyond diabetic peripheral neuropathy. Can J Diabetes. 2016;40(1):6-9. doi:10.1016/j.jcjd.2015.08.005 26778679
81 Horikawa C, Kodama S, Tanaka S, et al. Diabetes and risk of hearing impairment in adults: a meta-analysis. J Clin Endocrinol Metab. 2013;98(1):51-58. doi:10.1210/jc.2012-2119 23150692
82 Hicks CW, Wang D, Windham BG, Matsushita K, Selvin E. Prevalence of peripheral neuropathy defined by monofilament insensitivity in middle-aged and older adults in two US cohorts. Sci Rep. 2021;11(1):19159. doi:10.1038/s41598-021-98565-w 34580377
83 McDermott KM, Wang D, Windham BG, Schrack JA, Selvin E, Hicks CW. Peripheral neuropathy, gait speed, and lower extremity function in community-dwelling older adults with and without diabetes. J Am Geriatr Soc. 2024;72(10):3242-3245. doi:10.1111/jgs.19072 38994636
84 Hicks CW, Wang D, Daya N, et al. The association of peripheral neuropathy detected by monofilament testing with risk of falls and fractures in older adults. J Am Geriatr Soc. 2023;71(6):1902-1909. doi:10.1111/jgs.18338 36945108
85 Ward BK, Wenzel A, Kalyani RR, et al. Characterization of vestibulopathy in individuals with type 2 diabetes mellitus. Otolaryngol Head Neck Surg. 2015;153(1):112-118. doi:10.1177/0194599815576717 25829391
86 Agrawal Y, Carey JP, Della Santina CC, Schubert MC, Minor LB. Diabetes, vestibular dysfunction, and falls: analyses from the National Health and Nutrition Examination Survey. Otol Neurotol. 2010;31(9):1445-1450. doi:10.1097/MAO.0b013e3181f2f035 20856157
87 Hyams AV, Hay-McCutcheon M, Scogin F. Hearing and quality of life in older adults. J Clin Psychol. 2018;74(10):1874-1883. doi:10.1002/jclp.22648 29873396
88 Kabue S, Liu V, Dyer W, Raebel M, Nichols G, Schmittdiel J. Identifying common predictors of multiple adverse outcomes among elderly adults with type-2 diabetes. Med Care. 2019;57(9):702-709. doi:10.1097/MLR.0000000000001159 31356411
89 Li S, Pan S, Jiang S, Shin JI, Liu GG, Lyu B. Prescription medication use among patients with type 2 diabetes in the United States: 1999–2020. Diabetes Obes Metab. 2024;26(7):2933-2944. doi:10.1111/dom.15619 38695210
90 Vonna A, Salahudeen MS, Peterson GM. Adverse drug reaction-related hospital admissions in older adults with diabetes: incidence and implicated drug classes. Endocr Pract. 2025;31(11):1441-1448. doi:10.1016/j.eprac.2025.06.026 40617392
91 Chinmayee A, Subbarayan S, Myint PK, et al. Diabetes mellitus increases risk of adverse drug reactions and death in hospitalised older people: the SENATOR trial. Eur Geriatr Med. 2024;15(1):189-199. doi:10.1007/s41999-023-00903-w 38127206
92 Huang ES, Karter AJ, Danielson KK, Warton EM, Ahmed AT. The association between the number of prescription medications and incident falls in a multi-ethnic population of adult type-2 diabetes patients: the Diabetes and Aging Study. J Gen Intern Med. 2010;25(2):141-146. doi:10.1007/s11606-009-1179-2 19967465
93 Hirsch IB, Pihoker C, Roberts A, Zenno A, Le P. Medication use and self-care practices in persons with diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2024. https://www.ncbi.nlm.nih.gov/books/NBK607283/
94 Tang O, Matsushita K, Coresh J, et al. Mortality implications of prediabetes and diabetes in older adults. Diabetes Care. 2020;43(2):382-388. doi:10.2337/dc19-1221 31776141
95 Emerging Risk Factors Collaboration. Life expectancy associated with different ages at diagnosis of type 2 diabetes in high-income countries: 23 million person-years of observation. Lancet Diabetes Endocrinol. 2023;11(10):731-742. doi:10.1016/S2213-8587(23)00223-1 37708900
96 Gu K, Cowie CC, Harris MI. Mortality in adults with and without diabetes in a national cohort of the U.S. population, 1971–1993. Diabetes Care. 1998;21(7):1138-1145. doi:10.2337/diacare.21.7.1138 9653609
97 Rao Kondapally Seshasai S, Kaptoge S, Thompson A, et al. Diabetes mellitus, fasting glucose, and risk of cause-specific death. N Engl J Med. 2011;364(9):829-841. doi:10.1056/NEJMoa1008862 21366474
98 Tancredi M, Rosengren A, Svensson AM, et al. Excess mortality among persons with type 2 diabetes. N Engl J Med. 2015;373(18):1720-1732. doi:10.1056/NEJMoa1504347 26510021
99 Salehidoost R, Mansouri A, Amini M, Aminorroaya Yamini S, Aminorroaya A. Diabetes and all-cause mortality, a 18-year follow-up study. Sci Rep. 2020;10(1):3183. doi:10.1038/s41598-020-60142-y 32081921
100 Nanchen D, Rodondi N, Cornuz J, et al. Mortality associated with diabetes and cardiovascular disease in older women. PLoS One. 2012;7(11):e48818. doi:10.1371/journal.pone.0048818 23144985
101 Raghavan S, Vassy JL, Ho Y-L, et al. Diabetes mellitus-related all-cause and cardiovascular mortality in a national cohort of adults. J Am Heart Assoc. 2019;8(4):e011295. doi:10.1161/JAHA.118.011295 30776949
102 Campbell PT, Newton CC, Patel AV, Jacobs EJ, Gapstur SM. Diabetes and cause-specific mortality in a prospective cohort of one million U.S. adults. Diabetes Care. 2012;35(9):1835-1844. doi:10.2337/dc12-0002 22699290
103 Gregg EW, Pratt A, Owens A, et al. The burden of diabetes-associated multiple long-term conditions on years of life spent and lost. Nat Med. 2024;30(10):2830-2837. doi:10.1038/s41591-024-03123-2 39090411
104 Cheng YJ, Imperatore G, Geiss LS, et al. Trends and disparities in cardiovascular mortality among U.S. adults with and without self-reported diabetes, 1988–2015. Diabetes Care. 2018;41(11):2306-2315. doi:10.2337/dc18-0831 30131397
105 Fries JF. Aging, natural death, and the compression of morbidity. N Engl J Med. 1980;303(3):130-135. doi:10.1056/NEJM198007173030304 7383070
106 Garg P, Duggal N. Type 2 diabetes mellitus, its impact on quality of life and how the disease can be managed—a review. Obes Med. 2022;35:100459. doi:10.1016/j.obmed.2022.100459
107 Graham JE, Stoebner-May DG, Ostir GV, et al. Health related quality of life in older Mexican Americans with diabetes: a cross-sectional study. Health Qual Life Outcomes. 2007;5:39. doi:10.1186/1477-7525-5-39 17626634
108 Shao H, Yang S, Fonseca V, Stoecker C, Shi L. Estimating quality of life decrements due to diabetes complications in the United States: the Health Utility Index (HUI) Diabetes Complication Equation. Pharmacoeconomics. 2019;37(7):921-929. doi:10.1007/s40273-019-00775-8 30778865
109 Yang Y-C, Lin M-H, Wang C-S, et al. Geriatric syndromes and quality of life in older adults with diabetes. Geriatr Gerontol Int. 2019;19(6):518-524. doi:10.1111/ggi.13654 30957935
110 Laiteerapong N, Karter AJ, Liu JY, et al. Correlates of quality of life in older adults with diabetes: the Diabetes & Aging Study. Diabetes Care. 2011;34(8):1749-1753. doi:10.2337/dc10-2424 21636795
111 Karter AJ, Parker MM, Moffet HH, et al. Development and validation of the Life Expectancy Estimator for Older Adults with Diabetes (LEAD): the Diabetes and Aging Study. J Gen Intern Med. 2023;38(13):2860-2869. doi:10.1007/s11606-023-08219-y 37254010
112 Huang ES. Individualizing care for older adults with diabetes amid the revolution in pharmacotherapy. JAMA Intern Med. 2024;184(4):435-436. doi:10.1001/jamainternmed.2023.8559 38407838
113 Brown AF, Mangione CM, Saliba D, Sarkisian CA, California Healthcare Foundation/American Geriatrics Society Panel on Improving Care for Elders with Diabetes. Guidelines for Improving the Care of the Older Person with Diabetes Mellitus. J Am Geriatr Soc. 2003;51(5 Suppl Guidelines):S265-S280. doi:10.1046/j.1532-5415.51.5s.1.x
114 American Geriatrics Society Expert Panel on Care of Older Adults with Diabetes Mellitus, Moreno G, Mangione CM, Kimbro L, Vaisberg E. Guidelines abstracted from the American Geriatrics Society Guidelines for Improving the Care of Older Adults with Diabetes Mellitus: 2013 update. J Am Geriatr Soc. 2013;61(11):2020-2026. doi:10.1111/jgs.12514 24219204
115 Sinclair AJ, Paolisso G, Castro M, et al. European Diabetes Working Party for Older People 2011 Clinical Guidelines for Type 2 Diabetes Mellitus. Executive summary. Diabetes Metab. 2011;37(Suppl 3):S27-S38. doi:10.1016/S1262-3636(11)70962-4 22183418
116 American Diabetes Association Professional Practice Committee for Diabetes. 13. Older Adults: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S277-S296. doi:10.2337/dc26-S013 41358888
117 LeRoith D, Biessels GJ, Braithwaite SS, et al. Treatment of Diabetes in Older Adults: an Endocrine Society Clinical Practice Guideline. J Clin Endocrinol Metab. 2019;104(5):1520-1574. doi:10.1210/jc.2019-00198 30903688
118 Huang ES, Liu JY, Lipska KJ, et al. Data-driven classification of health status of older adults with diabetes: the Diabetes and Aging Study. J Am Geriatr Soc. 2023;71(7):2120-2130. doi:10.1111/jgs.18310 36883732
119 Leung V, Wroblewski K, Schumm LP, Huisingh-Scheetz M, Huang ES. Reexamining the classification of older adults with diabetes by comorbidities and exploring relationships with frailty, disability, and 5-year mortality. J Gerontol A Biol Sci Med Sci. 2021;76(11):2071-2079. doi:10.1093/gerona/glab141 34003280
120 Munshi M, Kahkoska AR, Neumiller JJ, et al. Realigning diabetes regimens in older adults: a 4S Pathway to guide simplification and deprescribing strategies. Lancet Diabetes Endocrinol. 2025;13(5):427-437. doi:10.1016/S2213-8587(24)00372-3 39978368
121 Knowler WC, Barrett-Connor E, Fowler SE, et al. Reduction in the incidence of type 2 diabetes with lifestyle intervention or metformin. N Engl J Med. 2002;346(6):393-403. doi:10.1056/NEJMoa012512 11832527
122 Diabetes Prevention Program Research Group, Knowler WC, Fowler SE, et al. 10-year follow-up of diabetes incidence and weight loss in the Diabetes Prevention Program Outcomes Study. Lancet. 2009;374(9702):1677-1686. doi:10.1016/S0140-6736(09)61457-4 19878986
123 Diabetes Prevention Program Research Group. Long-term effects of lifestyle intervention or metformin on diabetes development and microvascular complications over 15-year follow-up: the Diabetes Prevention Program Outcomes Study. Lancet Diabetes Endocrinol. 2015;3(11):866-875. doi:10.1016/S2213-8587(15)00291-0 26377054
124 Brown JS, Wing R, Barrett-Connor E, et al. Lifestyle intervention is associated with lower prevalence of urinary incontinence: the Diabetes Prevention Program. Diabetes Care. 2006;29(2):385-390. doi:10.2337/diacare.29.02.06.dc05-1781 16443892
125 Florez H, Pan Q, Ackermann RT, et al. Impact of lifestyle intervention and metformin on health-related quality of life: the Diabetes Prevention Program randomized trial. J Gen Intern Med. 2012;27(12):1594-1601. doi:10.1007/s11606-012-2122-5 22692637
126 Magkos F, Hjorth MF, Astrup A. Diet and exercise in the prevention and treatment of type 2 diabetes mellitus. Nat Rev Endocrinol. 2020;16(10):545-555. doi:10.1038/s41574-020-0381-5 32690918
127 Look AHEAD Research Group, Wing RR, Bolin P, et al. Cardiovascular effects of intensive lifestyle intervention in type 2 diabetes. N Engl J Med. 2013;369(2):145-154. doi:10.1056/NEJMoa1212914 23796131
128 Houston DK, Neiberg RH, Miller ME, et al. Physical function following a long-term lifestyle intervention among middle aged and older adults with type 2 diabetes: the Look AHEAD Study. J Gerontol A Biol Sci Med Sci. 2018;73(11):1552-1559. doi:10.1093/gerona/glx204 29053861
129 Kuna ST, Reboussin DM, Borradaile KE, et al. Long-term effect of weight loss on obstructive sleep apnea severity in obese patients with type 2 diabetes. Sleep. 2013;36(5):641-649. doi:10.5665/sleep.2618 23633746
130 Rubin RR, Wadden TA, Bahnson JL, et al. Impact of intensive lifestyle intervention on depression and health-related quality of life in type 2 diabetes: the Look AHEAD Trial. Diabetes Care. 2014;37(6):1544-1553. doi:10.2337/dc13-1928 24855155
131 Knowler WC, Chen H, Bahnson JL, et al. Within and post-trial effects of an intensive lifestyle intervention on kidney disease in adults with overweight or obesity and type 2 diabetes mellitus: a secondary analysis of the Look AHEAD clinical trial. BMJ Open Diabetes Res Care. 2024;12(3):e004079. doi:10.1136/bmjdrc-2024-004079 38816203
132 Rejeski WJ, Bray GA, Chen S-H, et al. Aging and physical function in type 2 diabetes: 8 years of an intensive lifestyle intervention. J Gerontol A Biol Sci Med Sci. 2015;70(3):345-353. doi:10.1093/gerona/glu083 24986062
133 Espeland MA, Rejeski WJ, West DS, et al. Intensive weight loss intervention in older individuals: results from the Action for Health in Diabetes type 2 diabetes mellitus trial. J Am Geriatr Soc. 2013;61(6):912-922. doi:10.1111/jgs.12271 23668423
134 Karter AJ, Parker MM, Moffet HH, Gilliam LK. Racial and ethnic differences in the association between mean glucose and hemoglobin A1c. Diabetes Technol Ther. 2023;25(10):697-704. doi:10.1089/dia.2023.0153 37535058
135 UK Prospective Diabetes Study Group. Effect of intensive blood-glucose control with metformin on complications in overweight patients with type 2 diabetes (UKPDS 34). UK Prospective Diabetes Study (UKPDS) Group. Lancet. 1998;352(9131):854-865. doi:10.1016/S0140-6736(98)07037-8 9742977
136 UK Prospective Diabetes Study Group. Intensive blood-glucose control with sulphonylureas or insulin compared with conventional treatment and risk of complications in patients with type 2 diabetes (UKPDS 33). UK Prospective Diabetes Study (UKPDS) Group. Lancet. 1998;352(9131):837-853. doi:10.1016/S0140-6736(98)07019-6 9742976
137 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA. 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med. 2008;359(15):1577-1589. doi:10.1056/NEJMoa0806470 18784090
138 Adler AI, Coleman RL, Leal J, Whiteley WN, Clarke P, Holman RR. Post-trial monitoring of a randomised controlled trial of intensive glycaemic control in type 2 diabetes extended from 10 years to 24 years (UKPDS 91). Lancet. 2024;404(10448):145-155. doi:10.1016/S0140-6736(24)00537-3 38772405
139 Action to Control Cardiovascular Risk in Diabetes Study Group, Gerstein HC, Miller ME, et al. Effects of intensive glucose lowering in type 2 diabetes. N Engl J Med. 2008;358(24):2545-2559. doi:10.1056/NEJMoa0802743 18539917
140 ACCORD Study Group, ACCORD Eye Study Group, Chew EY, et al. Effects of medical therapies on retinopathy progression in type 2 diabetes. N Engl J Med. 2010;363(3):233-244. doi:10.1056/NEJMoa1001288 20587587
141 Ismail-Beigi F, Craven T, Banerji MA, et al. Effect of intensive treatment of hyperglycaemia on microvascular outcomes in type 2 diabetes: an analysis of the ACCORD randomised trial. Lancet. 2010;376(9739):419-430. doi:10.1016/S0140-6736(10)60576-4 20594588
142 Miller ME, Bonds DE, Gerstein HC, et al. The effects of baseline characteristics, glycaemia treatment approach, and glycated haemoglobin concentration on the risk of severe hypoglycaemia: post hoc epidemiological analysis of the ACCORD study. BMJ. 2010;340:b5444. doi:10.1136/bmj.b5444 20061360
143 ACCORD Study Group. Nine-year effects of 3.7 years of intensive glycemic control on cardiovascular outcomes. Diabetes Care. 2016;39(5):701-708. doi:10.2337/dc15-2283 26822326
144 ADVANCE Collaborative Group, Patel A, MacMahon S, et al. Intensive blood glucose control and vascular outcomes in patients with type 2 diabetes. N Engl J Med. 2008;358(24):2560-2572. doi:10.1056/NEJMoa0802987 18539916
145 Zoungas S, Chalmers J, Neal B, et al. Follow-up of blood-pressure lowering and glucose control in type 2 diabetes. N Engl J Med. 2014;371(15):1392-1406. doi:10.1056/NEJMoa1407963 25234206
146 Duckworth W, Abraira C, Moritz T, et al. Glucose control and vascular complications in veterans with type 2 diabetes. N Engl J Med. 2009;360(2):129-139. doi:10.1056/NEJMoa0808431 19092145
147 Duckworth WC, Abraira C, Moritz TE, et al. The duration of diabetes affects the response to intensive glucose control in type 2 subjects: the VA Diabetes Trial. J Diabetes Complications. 2011;25(6):355-361. doi:10.1016/j.jdiacomp.2011.10.003 22055259
148 Hayward RA, Reaven PD, Wiitala WL, et al. Follow-up of glycemic control and cardiovascular outcomes in type 2 diabetes. N Engl J Med. 2015;372(23):2197-2206. doi:10.1056/NEJMoa1414266 26039600
149 Currie CJ, Peters JR, Tynan A, et al. Survival as a function of HbA(1c) in people with type 2 diabetes: a retrospective cohort study. Lancet. 2010;375(9713):481-489. doi:10.1016/S0140-6736(09)61969-3 20110121
150 Huang ES, Liu JY, Moffet HH, John PM, Karter AJ. Glycemic control, complications, and death in older diabetic patients: the Diabetes and Aging Study. Diabetes Care. 2011;34(6):1329-1336. doi:10.2337/dc10-2377 21505211
151 Schlender L, Martinez YV, Adeniji C, et al. Efficacy and safety of metformin in the management of type 2 diabetes mellitus in older adults: a systematic review for the development of recommendations to reduce potentially inappropriate prescribing. BMC Geriatr. 2017;17(Suppl 1):227. doi:10.1186/s12877-017-0574-5 29047344
152 Porter KM, Ward M, Hughes CF, et al. Hyperglycemia and metformin use are associated with B vitamin deficiency and cognitive dysfunction in older adults. J Clin Endocrinol Metab. 2019;104(10):4837-4847. doi:10.1210/jc.2018-01791 30920623
153 Alexopoulos AS, Kahkoska AR, Pate V, et al. Deintensification of treatment with sulfonylurea and insulin after severe hypoglycemia among older adults with diabetes. JAMA Netw Open. 2021;4(11):e2132215. doi:10.1001/jamanetworkopen.2021.32215 34726745
154 Zullo AR, Smith RJ, Gutman R, et al. Comparative safety of dipeptidyl peptidase-4 inhibitors and sulfonylureas among frail older adults. J Am Geriatr Soc. 2021;69(10):2923-2930. doi:10.1111/jgs.17371 34291453
155 van Dalem J, Brouwers MC, Stehouwer CD, et al. Risk of hypoglycaemia in users of sulphonylureas compared with metformin in relation to renal function and sulphonylurea metabolite group: population based cohort study. BMJ. 2016;354:i3625. doi:10.1136/bmj.i3625 27413017
156 Espeland MA, Pratley RE, Rosenstock J, et al. Cardiovascular outcomes and safety with linagliptin, a dipeptidyl peptidase-4 inhibitor, compared with the sulphonylurea glimepiride in older people with type 2 diabetes: a subgroup analysis of the randomized CAROLINA trial. Diabetes Obes Metab. 2021;23(2):569-580. doi:10.1111/dom.14254 33185002
157 Starup-Linde J, Gregersen S, Frost M, Vestergaard P. Use of glucose-lowering drugs and risk of fracture in patients with type 2 diabetes. Bone. 2017;95:136-142. doi:10.1016/j.bone.2016.11.026 27890548
158 Wondimkun YA, Caughey GE, Inacio MC, Air T, Sluggett JK. Cardiovascular safety of dipeptidyl peptidase 4 inhibitors compared with insulin or sulfonylureas added to metformin among older people with diabetes living in long-term care facilities. J Am Med Dir Assoc. 2025;26(12):105911. doi:10.1016/j.jamda.2025.105911 41075820
159 American Diabetes Association Professional Practice Committee for Diabetes. 9. Pharmacologic Approaches to Glycemic Treatment: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S183-S215. doi:10.2337/dc26-S009 41358900
160 Karagiannis T, Tsapas A, Athanasiadou E, et al. GLP-1 receptor agonists and SGLT2 inhibitors for older people with type 2 diabetes: a systematic review and meta-analysis. Diabetes Res Clin Pract. 2021;174:108737. doi:10.1016/j.diabres.2021.108737 33705820
161 Kutz A, Kim DH, Wexler DJ, et al. Comparative cardiovascular effectiveness and safety of SGLT-2 inhibitors, GLP-1 receptor agonists, and DPP-4 inhibitors according to frailty in type 2 diabetes. Diabetes Care. 2023;46(11):2004-2014. doi:10.2337/dc23-0671 37677118
162 Neeland IJ, Linge J, Birkenfeld AL. Changes in lean body mass with glucagon-like peptide-1-based therapies and mitigation strategies. Diabetes Obes Metab. 2024;26(Suppl 4):16-27. doi:10.1111/dom.15728 38937282
163 Jiang BC, Villareal DT. Weight loss-induced reduction of bone mineral density in older adults with obesity. J Nutr Gerontol Geriatr. 2019;38(1):100-114. doi:10.1080/21551197.2018.1564721 30794099
164 Dadwani RS, Wan W, Skandari MR, Huang ES. Expected health benefits of SGLT-2 inhibitors and GLP-1 receptor agonists in older adults. MDM Policy Pract. 2023;8(2):23814683231187566. doi:10.1177/23814683231187566 37492502
165 Desai RJ, Glynn RJ, Everett BM, et al. Comparative effectiveness of empagliflozin in reducing the burden of recurrent cardiovascular hospitalizations among older adults with diabetes in routine clinical care. Am Heart J. 2022;254:203-215. doi:10.1016/j.ahj.2022.09.008 36150454
166 Güdemann LM, Young KG, Thomas NJM, et al. Safety and effectiveness of SGLT2 inhibitors in a UK population with type 2 diabetes and aged over 70 years: an instrumental variable approach. Diabetologia. 2024;67(9):1817-1827. doi:10.1007/s00125-024-06190-9 38836934
167 Lin DS-H, Lee J-K, Chen W-J. Clinical adverse events associated with sodium-glucose cotransporter 2 inhibitors: a meta-analysis involving 10 randomized clinical trials and 71 553 individuals. J Clin Endocrinol Metab. 2021;106(7):2133-2145. doi:10.1210/clinem/dgab274 33895840
168 Fioretto P, Mansfield TA, Ptaszynska A, Yavin Y, Johnsson E, Parikh S. Long-term safety of dapagliflozin in older patients with type 2 diabetes mellitus: a pooled analysis of phase IIb/III studies. Drugs Aging. 2016;33(7):511-522. doi:10.1007/s40266-016-0382-1 27357173
169 Liu J, Li L, Li S, et al. Sodium-glucose co-transporter-2 inhibitors and the risk of diabetic ketoacidosis in patients with type 2 diabetes: a systematic review and meta-analysis of randomized controlled trials. Diabetes Obes Metab. 2020;22(9):1619-1627. doi:10.1111/dom.14075 32364674
170 Rong X, Li X, Gou Q, Liu K, Chen X. Risk of orthostatic hypotension associated with sodium-glucose cotransporter-2 inhibitor treatment: a meta-analysis of randomized controlled trials. Diab Vasc Dis Res. 2020;17(5):1479164120953625. doi:10.1177/1479164120953625 32981346
171 Zhuo M, Paik JM, Wexler DJ, Bonventre JV, Kim SC, Patorno E. SGLT2 inhibitors and the risk of acute kidney injury in older adults with type 2 diabetes. Am J Kidney Dis. 2022;79(6):858-867.e1. doi:10.1053/j.ajkd.2021.09.015 34762974
172 Patel A, ADVANCE Collaborative Group, MacMahon S, et al. Effects of a fixed combination of perindopril and indapamide on macrovascular and microvascular outcomes in patients with type 2 diabetes mellitus (the ADVANCE trial): a randomised controlled trial. Lancet. 2007;370(9590):829-840. doi:10.1016/S0140-6736(07)61303-8 17765963
173 Cooper-DeHoff RM, Gong Y, Handberg EM, et al. Tight blood pressure control and cardiovascular outcomes among hypertensive patients with diabetes and coronary artery disease. JAMA. 2010;304(1):61-68. doi:10.1001/jama.2010.884 20606150
174 ACCORD Study Group, Cushman WC, Evans GW, et al. Effects of intensive blood-pressure control in type 2 diabetes mellitus. N Engl J Med. 2010;362(17):1575-1585. doi:10.1056/NEJMoa1001286 20228401
175 Beddhu S, Chertow GM, Greene T, et al. Effects of intensive systolic blood pressure lowering on cardiovascular events and mortality in patients with type 2 diabetes mellitus on standard glycemic control and in those without diabetes mellitus: reconciling results from ACCORD BP and SPRINT. J Am Heart Assoc. 2018;7(18):e009326. doi:10.1161/JAHA.118.009326 30371182
176 Bi Y, Li M, Liu Y, et al. Intensive blood-pressure control in patients with type 2 diabetes. N Engl J Med. 2025;392(12):1155-1167. doi:10.1056/NEJMoa2412006 39555827
177 Shepherd J, Blauw GJ, Murphy MB, et al. Pravastatin in elderly individuals at risk of vascular disease (PROSPER): a randomised controlled trial. Lancet. 2002;360(9346):1623-1630. doi:10.1016/s0140-6736(02)11600-x 12457784
178 Collins R, Armitage J, Parish S, Sleigh P, Peto R, Heart Protection Study Collaborative Group. MRC/BHF Heart Protection Study of cholesterol-lowering with simvastatin in 5963 people with diabetes: a randomised placebo-controlled trial. Lancet. 2003;361(9374):2005-2016. doi:10.1016/s0140-6736(03)13636-7 12814710
179 Neil HA, DeMicco DA, Luo D, et al. Analysis of efficacy and safety in patients aged 65–75 years at randomization: Collaborative Atorvastatin Diabetes Study (CARDS). Diabetes Care. 2006;29(11):2378-2384. doi:10.2337/dc06-0872 17065671
180 Ouchi Y, Sasaki J, Arai H, et al. Ezetimibe Lipid-Lowering Trial on Prevention of Atherosclerotic Cardiovascular Disease in 75 or Older (EWTOPIA 75): a randomized, controlled trial. Circulation. 2019;140(12):992-1003. doi:10.1161/CIRCULATIONAHA.118.039415 31434507
181 Imbalzano E, Ilardi F, Orlando L, Pintaudi B, Savarese G, Rosano G. The efficacy of PCSK9 inhibitors on major cardiovascular events and lipid profile in patients with diabetes: a systematic review and meta-analysis of randomized controlled trials. Eur Heart J Cardiovasc Pharmacother. 2023;9(4):318-327. doi:10.1093/ehjcvp/pvad019 36972610
182 Al Said S, O’Donoghue ML, Ran X, et al. Long-term lipid lowering with evolocumab in older individuals. J Am Coll Cardiol. 2025;85(5):504-512. doi:10.1016/j.jacc.2024.11.019 39909681
183 Ray KK, Nicholls SJ, Li N, et al. Efficacy and safety of bempedoic acid among patients with and without diabetes: prespecified analysis of the CLEAR Outcomes randomised trial. Lancet Diabetes Endocrinol. 2024;12(1):19-28. doi:10.1016/S2213-8587(23)00316-9 38061370
184 McNeil JJ, Wolfe R, Woods RL, et al. Effect of aspirin on cardiovascular events and bleeding in the healthy elderly. N Engl J Med. 2018;379(16):1509-1518. doi:10.1056/NEJMoa1805819 30221597
185 Papazafiropoulou AK, Melidonis A, Antonopoulos S. Aspirin in primary prevention of cardiovascular disease in diabetes. Arch Med Sci Atheroscler Dis. 2021;6(1):e109-e114. doi:10.5114/amsad.2021.105596 36161214
186 Kazibwe R, Singleton M, Bancks MP, et al. Efficacy of aspirin for primary prevention among adults with high-risk type 2 diabetes in the ACCORD trial. Diabetes Obes Metab. 2024;26(9):4011-4018. doi:10.1111/dom.15753 38984384
187 ASCEND Study Collaborative Group, Bowman L, Mafham M, et al. Effects of aspirin for primary prevention in persons with diabetes mellitus. N Engl J Med. 2018;379(16):1529-1539. doi:10.1056/NEJMoa1804988 30146931
188 American Diabetes Association Professional Practice Committee for Diabetes. 10. Cardiovascular Disease and Risk Management: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S216-S245. doi:10.2337/dc26-S010 41358899
189 Polonsky WH, Peters AL, Hessler D. The impact of real-time continuous glucose monitoring in patients 65 years and older. J Diabetes Sci Technol. 2016;10(4):892-897. doi:10.1177/1932296816643542 27022095
190 Pratley RE, Kanapka LG, Rickels MR, et al. Effect of continuous glucose monitoring on hypoglycemia in older adults with type 1 diabetes: a randomized clinical trial. JAMA. 2020;323(23):2397-2406. doi:10.1001/jama.2020.6928 32543682
191 Ruedy KJ, Parkin CG, Riddlesworth TD, Graham C, DIAMOND Study Group. Continuous glucose monitoring in older adults with type 1 and type 2 diabetes using multiple daily injections of insulin: results from the DIAMOND trial. J Diabetes Sci Technol. 2017;11(6):1138-1146. doi:10.1177/1932296817704445 28449590
192 Huang ES, Sinclair A, Conlin PR, et al. The growing role of technology in the care of older adults with diabetes. Diabetes Care. 2023;46(8):1455-1463. doi:10.2337/dci23-0021 37471606
193 Stone MP, Agrawal P, Chen X, et al. Retrospective analysis of 3-month real-world glucose data after the MiniMed 670G system commercial launch. Diabetes Technol Ther. 2018;20(10):689-692. doi:10.1089/dia.2018.0202 30160523
194 McAuley SA, Trawley S, Vogrin S, et al. Closed-loop insulin delivery versus sensor-augmented pump therapy in older adults with type 1 diabetes (ORACL): a randomized, crossover trial. Diabetes Care. 2022;45(2):381-390. doi:10.2337/dc21-1667 34844995
195 Boughton CK, Hartnell S, Thabit H, et al. Hybrid closed-loop glucose control compared with sensor augmented pump therapy in older adults with type 1 diabetes: an open-label multicentre, multinational, randomised, crossover study. Lancet Healthy Longev. 2022;3(3):e135-e142. doi:10.1016/S2666-7568(22)00005-8 35359882
196 Lee JJN, Abdul Aziz A, Chan ST, et al. Effects of mobile health interventions on health-related outcomes in older adults with type 2 diabetes: a systematic review and meta-analysis. J Diabetes. 2023;15(1):47-57. doi:10.1111/1753-0407.13346 36649940
197 Marsh Z, Nguyen Y, Teegala Y, Cotter VT. Diabetes management among underserved older adults through telemedicine and community health workers. J Am Assoc Nurse Pract. 2021;34(1):26-31. doi:10.1097/JXX.0000000000000595 33859074
198 Campos BM, Kieffer EC, Sinco B, Palmisano G, Spencer MS, Piatt GA. Effectiveness of a community health worker-led diabetes intervention among older and younger Latino participants: results from a randomized controlled trial. Geriatrics (Basel). 2018;3(3):47. doi:10.3390/geriatrics3030047 30345345
199 Kramer MK, Vanderwood KK, Arena VC, et al. Evaluation of a Diabetes Prevention Program lifestyle intervention in older adults: a randomized controlled study in three senior/community centers of varying socioeconomic status. Diabetes Educ. 2018;44(2):118-129. doi:10.1177/0145721718759982 29514568
200 Illinois Pathways to Health. Supporting Healthier Aging Across Illinois. 2026. Accessed March 5, 2026. https://www.ilpathwaystohealth.org/
201 Northwood M, Shah AQ, Abeygunawardena C, Garnett A, Schumacher C. Care coordination of older adults with diabetes: a scoping review. Can J Diabetes. 2023;47(3):272-286. doi:10.1016/j.jcjd.2022.11.004 36517260
202 Launer LJ, Miller ME, Williamson JD, et al. Effects of intensive glucose lowering on brain structure and function in people with type 2 diabetes (ACCORD MIND): a randomised open-label substudy. Lancet Neurol. 2011;10(11):969-977. doi:10.1016/S1474-4422(11)70188-0 21958949
203 Murray AM, Hsu FC, Williamson JD, et al. ACCORDION MIND: results of the observational extension of the ACCORD MIND randomised trial. Diabetologia. 2017;60(1):69-80. doi:10.1007/s00125-016-4118-x 27766347
204 Sun M, Wang X, Lu Z, et al. Evaluating GLP-1 receptor agonists versus metformin as first-line therapy for reducing dementia risk in type 2 diabetes. BMJ Open Diabetes Res Care. 2025;13(4):e004902. doi:10.1136/bmjdrc-2025-004902 40695613
205 Nance N, Gilsanz P, Karter AJ, et al. GLP-1RA comparative effectiveness against dementia onset relative to other antidiabetic medications in a large, multi-site cohort of patients with type 2 diabetes. Alzheimers Dement. 2025;21(9):e70621. doi:10.1002/alz.70621 40952016
206 Kim HK, Biessels GJ, Yu MH, et al. SGLT2 inhibitor use and risk of dementia and Parkinson disease among patients with type 2 diabetes. Neurology. 2024;103(8):e209805. doi:10.1212/WNL.0000000000209805 39292986
207 Borson S, Scanlan JM, Chen P, Ganguli M. The Mini-Cog as a screen for dementia: validation in a population-based sample. J Am Geriatr Soc. 2003;51(10):1451-1454. doi:10.1046/j.1532-5415.2003.51465.x 14511167
208 Folstein MF, Folstein SE, McHugh PR. “Mini-Mental State”. A practical method for grading the cognitive state of patients for the clinician. J Psychiatr Res. 1975;12(3):189-198. doi:10.1016/0022-3956(75)90026-6 1202204
209 Nasreddine ZS, Phillips NA, Bédirian V, et al. The Montreal Cognitive Assessment, MoCA: a brief screening tool for mild cognitive impairment. J Am Geriatr Soc. 2005;53(4):695-699. doi:10.1111/j.1532-5415.2005.53221.x 15817019
210 Montero-Odasso M, van der Velde N, Martin FC, et al. World guidelines for falls prevention and management for older adults: a global initiative. Age Ageing. 2022;51(9):afac205. doi:10.1093/ageing/afac205 36178003
211 Panel on Prevention of Falls in Older Persons of the American Geriatrics Society and British Geriatrics Society. Summary of the updated American Geriatrics Society/British Geriatrics Society Clinical Practice Guideline for Prevention of Falls in Older Persons. J Am Geriatr Soc. 2011;59(1):148-157. doi:10.1111/j.1532-5415.2010.03234.x 21226685
212 US Preventive Services Task Force, Nicholson WK, Silverstein M, et al. Interventions to Prevent Falls in Community-Dwelling Older Adults: US Preventive Services Task Force Recommendation Statement. JAMA. 2024;332(1):51-57. doi:10.1001/jama.2024.8481 38833246
213 Sherrington C, Fairhall NJ, Wallbank GK, et al. Exercise for preventing falls in older people living in the community. Cochrane Database Syst Rev. 2019;1(1):CD012424. doi:10.1002/14651858.CD012424.pub2 30703272
214 Zhang H, Xing Y, Zhang Y, et al. Association between depression and quality of life in older adults with type 2 diabetes: a moderated mediation of cognitive impairment and sleep quality. J Affect Disord. 2023;340:17-24. doi:10.1016/j.jad.2023.07.105 37506770
215 Rinaldi P, Mecocci P, Benedetti C, et al. Validation of the five-item Geriatric Depression Scale in elderly subjects in three different settings. J Am Geriatr Soc. 2003;51(5):694-698. doi:10.1034/j.1600-0579.2003.00216.x 12752847
216 Davies LE, Spiers G, Kingston A, Todd A, Adamson J, Hanratty B. Adverse outcomes of polypharmacy in older people: systematic review of reviews. J Am Med Dir Assoc. 2020;21(2):181-187. doi:10.1016/j.jamda.2019.10.022 31926797
217 Thompson W, McDonald EG. Polypharmacy and deprescribing in older adults. Annu Rev Med. 2024;75(1):113-127. doi:10.1146/annurev-med-070822-101947 37729029
218 American Geriatrics Society Beers Criteria® Update Expert Panel. American Geriatrics Society 2023 updated AGS Beers Criteria® for potentially inappropriate medication use in older adults. J Am Geriatr Soc. 2023;71(7):2052-2081. doi:10.1111/jgs.18372 37139824
219 O’Mahony D, Cherubini A, Guiteras AR, et al. STOPP/START criteria for potentially inappropriate prescribing in older people: version 3. Eur Geriatr Med. 2023;14(4):625-632. doi:10.1007/s41999-023-00777-y 37256475
220 Whitmer RA, Karter AJ, Yaffe K, Quesenberry CP, Jr., Selby JV. Hypoglycemic episodes and risk of dementia in older patients with type 2 diabetes mellitus. JAMA. 2009;301(15):1565-1572. doi:10.1001/jama.2009.460 19366776
221 Bonds DE, Miller ME, Bergenstal RM, et al. The association between symptomatic, severe hypoglycaemia and mortality in type 2 diabetes: retrospective epidemiological analysis of the ACCORD study. BMJ. 2010;340:b4909. doi:10.1136/bmj.b4909 20061358
222 Hope SV, Taylor PJ, Shields BM, Hattersley AT, Hamilton W. Are we missing hypoglycaemia? Elderly patients with insulin-treated diabetes present to primary care frequently with non-specific symptoms associated with hypoglycaemia. Prim Care Diabetes. 2018;12(2):139-146. doi:10.1016/j.pcd.2017.08.004 28918198
223 Lipska KJ, Ross JS, Wang Y, et al. National trends in US hospital admissions for hyperglycemia and hypoglycemia among Medicare beneficiaries, 1999 to 2011. JAMA Intern Med. 2014;174(7):1116-1124. doi:10.1001/jamainternmed.2014.1824 24838229
224 Geller AI, Shehab N, Lovegrove MC, et al. National estimates of insulin-related hypoglycemia and errors leading to emergency department visits and hospitalizations. JAMA Intern Med. 2014;174(5):678-686. doi:10.1001/jamainternmed.2014.136 24615164
225 Karter AJ, Moffet HH, Liu JY, Lipska KJ. Surveillance of hypoglycemia—limitations of emergency department and hospital utilization data. JAMA Intern Med. 2018;178(7):987-988. doi:10.1001/jamainternmed.2018.1014 29710182
226 Arnold SV, Lipska KJ, Wang J, Seman L, Mehta SN, Kosiborod M. Use of intensive glycemic management in older adults with diabetes mellitus. J Am Geriatr Soc. 2018;66(6):1190-1194. doi:10.1111/jgs.15335 29633237
227 Karter AJ, Warton EM, Lipska KJ, et al. Development and validation of a tool to identify patients with type 2 diabetes at high risk of hypoglycemia-related emergency department or hospital use. JAMA Intern Med. 2017;177(10):1461-1470. doi:10.1001/jamainternmed.2017.3844 28828479
228 Grant RW, Peterson I, McCloskey JM, et al. Diabetes deprescribing in older adults: a randomized clinical trial. JAMA Intern Med. 2025;185(8):926-935. doi:10.1001/jamainternmed.2025.2015 40549370
229 Crutzen S, Baas G, Denig P, Heringa M, Taxis K. Pharmacist-led intervention aimed at deprescribing and appropriate use of cardiometabolic medication among people with type 2 diabetes. Res Social Adm Pharm. 2023;19(5):783-792. doi:10.1016/j.sapharm.2022.11.009 36740525
230 Abou J, Elders PJM, Huijts D, van Marum R, Hugtenburg J. Pharmacist-led deprescribing of cardiovascular and diabetes medication within a clinical medication review: the LeMON study (Less Medicines in Older Patients in the Netherlands), a cluster randomized controlled trial. Int J Clin Pharm. 2025;47(3):717-725. doi:10.1007/s11096-025-01863-w 39847313
231 Alvarez G, Minova L, Bente J. Impact of pharmacist-led deprescribing on inappropriate rapid-acting insulin use among admitted older adults. Clin Diabetes. 2025;43(5):805-812. doi:10.2337/cd25-0062 41438318
232 Casagrande SS, Park J, Herman WH, Bullard KM. Health insurance and diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK); 2023. https://www.ncbi.nlm.nih.gov/books/NBK597725/
233 Ashkenazy R, Abrahamson MJ. Medicare coverage for patients with diabetes. A national plan with individual consequences. J Gen Intern Med. 2006;21(4):386-392. doi:10.1111/j.1525-1497.2006.00403.x 16686819
234 Galindo RJ, Parkin CG, Aleppo G, et al. What’s wrong with this picture? A critical review of current Centers for Medicare & Medicaid Services coverage criteria for continuous glucose monitoring. Diabetes Technol Ther. 2021;23(9):652-660. doi:10.1089/dia.2021.0107 33844588
235 Ritchie ND, Turk MT. Enhancing access and impact of the Medicare Diabetes Prevention Program using telehealth: a narrative review. Mhealth. 2024;10:10. doi:10.21037/mhealth-23-37 38323146
236 Parker ED, Lin J, Mahoney T, et al. Economic costs of diabetes in the U.S. in 2022. Diabetes Care. 2024;47(1):26-43. doi:10.2337/dci23-0085 37909353
237 Langa KM, Vijan S, Hayward RA, et al. Informal caregiving for diabetes and diabetic complications among elderly Americans. J Gerontol B Psychol Sci Soc Sci. 2002;57(3):S177-S186. doi:10.1093/geronb/57.3.s177 11983744
238 Huang ES, Basu A, O’Grady M, Capretta JC. Projecting the future diabetes population size and related costs for the U.S. Diabetes Care. 2009;32(12):2225-2229. doi:10.2337/dc09-0459 19940225
239 Johnston R, Uthman O, Cummins E, et al. Canagliflozin, dapagliflozin and empagliflozin monotherapy for treating type 2 diabetes: systematic review and economic evaluation. Health Technol Assess. 2017;21(2):1-218. doi:10.3310/hta21020 28105986
240 Hwang JH, Laiteerapong N, Huang ES, Kim DD. Lifetime health effects and cost-effectiveness of tirzepatide and semaglutide in US adults. JAMA Health Forum. 2025;6(3):e245586. doi:10.1001/jamahealthforum.2024.5586 40085108
241 Choi JG, Winn AN, Skandari MR, et al. First-line therapy for type 2 diabetes with sodium-glucose cotransporter-2 inhibitors and glucagon-like peptide-1 receptor agonists: a cost-effectiveness study. Ann Intern Med. 2022;175(10):1392-1400. doi:10.7326/M21-2941 36191315
242 Berwick DM. Launching accountable care organizations—the proposed rule for the Medicare Shared Savings Program. N Engl J Med. 2011;364(16):e32. doi:10.1056/NEJMp1103602 21452999
243 Fraze TK, Lewis VA, Tierney E, Colla CH. Quality of care improves for patients with diabetes in Medicare Shared Savings accountable care organizations: organizational characteristics associated with performance. Popul Health Manag. 2018;21(5):401-408. doi:10.1089/pop.2017.0102 29211623
244 McWilliams JM, Chernew ME, Landon BE, Schwartz AL. Performance differences in year 1 of pioneer accountable care organizations. N Engl J Med. 2015;372(20):1927-1936. doi:10.1056/NEJMsa1414929 25875195
245 McWilliams JM, Hatfield LA, Landon BE, Hamed P, Chernew ME. Medicare spending after 3 years of the Medicare Shared Savings Program. N Engl J Med. 2018;379(12):1139-1149. doi:10.1056/NEJMsa1803388 30183495
246 McWilliams JM, Hatfield LA, Chernew ME, Landon BE, Schwartz AL. Early performance of accountable care organizations in Medicare. N Engl J Med. 2016;374(24):2357-2366. doi:10.1056/NEJMsa1600142 27075832
247 Trombley MJ, Fout B, Brodsky S, McWilliams JM, Nyweide DJ, Morefield B. Early effects of an accountable care organization model for underserved areas. N Engl J Med. 2019;381(6):543-551. doi:10.1056/NEJMsa1816660 31291511
248 Burton RA, Lallemand NM, Peters RA, Zuckerman S, MAPCP Demonstration Evaluation Team. Characteristics of patient-centered medical home initiatives that generated savings for Medicare: a qualitative multi-case analysis. J Gen Intern Med. 2018;33(7):1028-1034. doi:10.1007/s11606-018-4309-x 29404947
249 Bojadzievski T, Gabbay RA. Patient-centered medical home and diabetes. Diabetes Care. 2011;34(4):1047-1053. doi:10.2337/dc10-1671 21447667
250 Carlin CS, Peterson K, Solberg LI. The impact of patient-centered medical home certification on quality of care for patients with diabetes. Health Serv Res. 2021;56(3):352-362. doi:10.1111/1475-6773.13588 33135203
251 Dobbins JM, Peiper N, Jones E, Clayton R, Peterson LE, Phillips RL, Jr. Patient-centered medical home recognition and diabetes control among health centers: exploring the role of enabling services. Popul Health Manag. 2018;21(1):6-12. doi:10.1089/pop.2017.0001 28467266
252 Niazi SK. The Inflation Reduction Act: a boon for the generic and biosimilar industry. J Clin Pharm Ther. 2022;47(11):1738-1751. doi:10.1111/jcpt.13783 36207987
253 Kazi DS, Wadhera RK, Rome BN. The Inflation Reduction Act and access to high-cost cardiovascular therapies. JAMA. 2023;330(17):1619-1620. doi:10.1001/jama.2023.19129 37728949
254 Myerson R, Qato DM, Goldman DP, Romley JA. Insulin fills by Medicare enrollees and out-of-pocket caps under the Inflation Reduction Act. JAMA. 2023;330(7):660-662. doi:10.1001/jama.2023.12951 37486673

FIGURE 1.

Trends in the Prevalence of Diagnosed Diabetes Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2000–2023.

Diagnosed diabetes is self-reported.

SOURCE: National Health Interview Surveys 2000–2023

Line graph showing that the prevalence of diagnosed diabetes has increased from 14 percent in 2000 and to 20 percent in 2023 among adults 65 years of age or older.

FIGURE 2.

Trends in the Number of Adults Age ≥60 Years With Diagnosed Diabetes, by Age, U.S., 2000–2023.

Diagnosed diabetes is self-reported.

* NHIS weighted estimates

SOURCE: National Health Interview Surveys (NHIS) 2000–2023

Line graph showing that the number of older adults with diagnosed diabetes has increased from about 5 million in 2000 to 12 million in 2023 among adults 65 years of age or older.

FIGURE 3.

Duration of Diabetes Among Adults Age ≥60 Years, by Age, U.S., 2022–2023.

Data are self-reported.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that the majority of older adults have had a duration of diabetes of 10 years or longer.

FIGURE 4.

Body Mass Index Distribution Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023.

Diagnosed diabetes is self-reported. Body mass index (BMI), based on weight and height measured in a standardized physical examination, is defined as: underweight, <18.5 kg/m^2^; healthy weight, 18.5–<25 kg/m^2^; overweight, 25–<30 kg/m^2^; obese, ≥30 kg/m^2^, except for non-Hispanic Asian adults where categories are defined as underweight, <18.5 kg/m^2^; healthy weight, 18.5–22.9 kg/m^2^; overweight, 23.0–27.4 kg/m^2^; obese, ≥27.5 kg/m^2^. Error bars represent 95% confidence intervals.

^1^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

Bar graph showing that 53 percent of older adults with diabetes were obese compared to 36 percent of older adults without diabetes.

FIGURE 5.

Body Mass Index Distribution Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023.

Diagnosed diabetes is self-reported. Body mass index (BMI), based on self-reported weight and height, is defined as: underweight, <18.5 kg/m^2^; healthy weight, 18.5–<25 kg/m^2^; overweight, 25–<30 kg/m^2^; obese, ≥30 kg/m^2^ except for non-Hispanic Asian adults where categories are defined as underweight, <18.5 kg/m^2^; healthy weight, 18.5–22.9 kg/m^2^; overweight, 23.0–27.4 kg/m^2^; obese, ≥27.5 kg/m^2^.

^1^ Relative standard error >30%–40% for underweight among those ages 60–69 and 70–79 years.

^2^ Relative standard error >50% for underweight among those age ≥80 years.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that among older adults with diabetes, 55 percent age 60 to 69 years were obese compared to 34 percent age 80 years or older.

FIGURE 6.

Cardiovascular Complications Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023.

Data are self-reported. “Any heart condition” includes congestive heart failure, coronary heart disease, or heart attack. Error bars represent 95% confidence intervals.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

Bar graph showing that a history of cardiovascular complications among older adults is more prevalent among those with diabetes compared to those without diabetes.

FIGURE 7.

Cardiovascular Complications Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023.

Data are self-reported. Error bars represent 95% confidence intervals.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that history of coronary heart disease is the most prevalent cardiovascular complication among older adults with diabetes and cardiovascular complications increase with age.

FIGURE 8.

Microvascular Complications Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023.

Diagnosed diabetes is self-reported. A conversion formula for albumin-to-creatinine ratios is available in the Conversions section. Error bars represent 95% confidence intervals.

* Retinopathy is self-reported and only asked among those with diagnosed diabetes in the NHANES 2017–2020; retinopathy was not included in the 2021–2023 survey cycles.

^†^ Moderately elevated albuminuria is defined as albumin-to-creatinine ratio 30–300 mg/g.

^‡^ Decreased kidney function is based on estimated glomerular filtration rate (eGFR) <60 mL/min/1.73 m^2^ determined using the CKD-EPI Creatinine Equation 2021.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2017–2023

Bar graph showing that microalbuminuria and decreased kidney function are more prevalent among older adults with diabetes compared to those without diabetes and 18 percent with diabetes reported retinopathy.

FIGURE 9.

Vision Complications Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023.

Data are self-reported. Error bars represent 95% confidence intervals.

* Trouble seeing includes self-reporting some difficulty, a lot of difficulty, or cannot do at all with respect to seeing even when wearing glasses or contact lenses.

^†^ Blindness includes self-reporting cannot do at all with respect to seeing even when wearing glasses or contact lenses among those who reported trouble seeing.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2022–2023

Bar graph showing that 29 percent of older adults age 65 years or older with diabetes reported trouble seeing with little difference by 10 year age groups.

FIGURE 10.

Chronic Pain Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2023.

Data are self-reported. Error bars represent 95% confidence intervals.

* Any pain is defined as reporting pain in the past 3 months on most days or every day. Pain by location is among those reporting pain some days, most days, or every day in the past 3 months. People reporting “a lot” or “somewhere in between a little and a lot” of pain were determined to have pain at that location.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Survey 2023

Bar graph showing that 45 percent of adults age 65 years or older with diabetes reported any type of chronic pain with hip, hand, and back pain being the most common pain sites.

TABLE 1.

Prevalence of Diagnosed Diabetes, by Age and Sex, U.S., 2022–2023

AGE (YEARS) AND SEX | DIAGNOSED DIABETES (TOTAL U.S. POPULATION)
AGE (YEARS) AND SEX | N (millions)* | Percent (Standard Error)
Total
≥65 | 11.6 | 20.3 (0.4)
60–69 | 7.01 | 17.6 (0.4)
70–79 | 5.71 | 21.7 (0.5)
≥80 | 2.41 | 19.0 (0.7)
Men
≥65 | 5.71 | 22.0 (0.6)
60–69 | 3.56 | 18.6 (0.6)
70–79 | 2.84 | 23.3 (0.8)
≥80 | 1.13 | 22.2 (1.2)
Women
≥65 | 5.89 | 18.9 (0.5)
60–69 | 3.46 | 16.8 (0.6)
70–79 | 2.87 | 20.4 (0.7)
≥80 | 1.28 | 16.9 (0.9)

Diagnosed diabetes is self-reported.

* NHIS weighted estimates

SOURCE: National Health Interview Surveys (NHIS) 2022–2023

TABLE 2.

Trends in the Percent Distribution of Age Among Adults Age ≥18 Years With Diabetes, U.S., 2000–2023

YEAR | PERCENT (STANDARD ERROR)
YEAR | Age (Years)
YEAR | ≥65 | 18–59 | 60–69 | 70–79 | ≥80
2000 | 40.2 (1.3) | 48.3 (1.3) | 23.2 (1.1) | 21.4 (1.0) | 7.1 (0.6)
2001 | 38.5 (1.1) | 49.3 (1.2) | 23.3 (1.0) | 20.0 (1.0) | 7.4 (0.6)
2002 | 39.4 (1.1) | 48.7 (1.3) | 23.8 (1.0) | 20.1 (1.0) | 7.4 (0.6)
2003 | 40.5 (1.3) | 48.0 (1.3) | 24.0 (1.0) | 19.2 (0.9) | 8.8 (0.7)
2004 | 39.6 (1.1) | 47.6 (1.2) | 24.8 (1.0) | 19.1 (0.9) | 8.4 (0.6)
2005 | 36.8 (1.1) | 50.4 (1.2) | 23.5 (1.0) | 17.8 (0.8) | 8.2 (0.6)
2006 | 37.6 (1.4) | 49.2 (1.5) | 24.1 (1.2) | 17.7 (1.0) | 9.0 (0.7)
2007 | 39.1 (1.3) | 47.5 (1.3) | 25.9 (1.2) | 18.0 (1.0) | 8.7 (0.8)
2008 | 36.8 (1.3) | 49.1 (1.5) | 25.7 (1.2) | 16.5 (1.0) | 8.7 (0.7)
2009 | 36.0 (1.3) | 50.4 (1.3) | 24.3 (1.1) | 16.7 (0.9) | 8.6 (0.6)
2010 | 39.5 (1.2) | 45.2 (1.2) | 26.9 (0.9) | 19.0 (0.9) | 8.9 (0.6)
2011 | 39.7 (1.0) | 44.8 (1.1) | 28.3 (0.9) | 18.1 (0.7) | 8.8 (0.6)
2012 | 39.3 (1.1) | 44.9 (1.1) | 28.8 (1.0) | 17.3 (0.8) | 9.0 (0.6)
2013 | 41.0 (1.0) | 44.2 (1.1) | 27.9 (1.0) | 17.9 (0.8) | 10.0 (0.6)
2014 | 42.1 (1.2) | 43.7 (1.2) | 28.2 (1.0) | 19.8 (0.9) | 8.4 (0.6)
2015 | 43.6 (1.2) | 41.1 (1.2) | 30.2 (1.1) | 19.0 (0.9) | 9.7 (0.7)
2016 | 42.8 (1.1) | 42.7 (1.2) | 29.8 (1.0) | 19.2 (0.8) | 8.3 (0.5)
2017 | 40.9 (1.2) | 42.7 (1.3) | 29.2 (1.1) | 19.5 (0.8) | 8.6 (0.6)
2018 | 44.0 (1.1) | 41.9 (1.2) | 28.1 (1.0) | 20.7 (0.8) | 9.2 (0.6)
2019 | 45.4 (1.1) | 39.4 (1.0) | 28.3 (0.9) | 22.4 (0.8) | 9.9 (0.6)
2020 | 48.5 (1.2) | 38.0 (1.1) | 28.5 (1.0) | 23.0 (0.8) | 10.5 (0.6)
2021 | 44.7 (1.0) | 40.6 (1.1) | 27.5 (0.9) | 22.4 (0.8) | 9.4 (0.6)
2022 | 46.4 (1.1) | 39.1 (1.1) | 28.1 (0.9) | 23.1 (0.9) | 9.8 (0.6)
2023 | 47.1 (1.1) | 39.0 (1.1) | 28.4 (0.9) | 23.0 (0.8) | 9.6 (0.6)

Diagnosed diabetes is self-reported.

SOURCE: National Health Interview Surveys 2000–2023

TABLE 3.

Prevalence of Undiagnosed Diabetes and Prediabetes Among Adults Age ≥60 Years, by Age and Sex, U.S., 2017–2023

AGE (YEARS) AND SEX | PERCENT (STANDARD ERROR)
AGE (YEARS) AND SEX | Diagnosed Diabetes* | Undiagnosed Diabetes^†^ | Prediabetes^‡^ | Normal Glucose^§^
Total
≥65 | 23.1 (1.1) | 7.0 (0.6) | 53.9 (1.4) | 15.9 (1.4)
60–69 | 20.0 (1.3) | 6.9 (1.0) | 53.9 (1.6) | 19.2 (1.3)
70–79 | 24.1 (1.5) | 7.0 (1.0) | 53.0 (2.2) | 15.9 (2.2)
≥80 | 23.4 (1.8) | 8.4 (1.4) | 52.9 (2.1) | 15.3 (1.7)
Men
≥65 | 26.9 (1.3) | 7.0 (1.0) | 54.5 (1.8) | 11.6 (1.5)
60–69 | 23.7 (1.9) | 7.2 (1.7) | 55.3 (2.4) | 13.7 (1.9)
70–79 | 27.9 (1.9) | 7.7 (1.4) | 54.3 (3.0) | 10.1 (1.7)
≥80 | 26.2 (2.4) | 7.4 (1.6) | 54.4 (3.1) | 12.0 (2.5)
Women
≥65 | 20.1 (1.5) | 7.0 (1.0) | 53.5 (1.9) | 19.4 (2.4)
60–69 | 16.5 (1.4) | 6.6 (1.0) | 52.6 (2.0) | 24.3 (2.0)
70–79 | 21.1 (1.9) | 6.3 (1.5) | 52.1 (2.8) | 20.5 (3.4)
≥80 | 21.4 (2.4) | 9.1 (2.2) | 51.9 (3.0) | 17.6 (2.9)

Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; FPG, fasting plasma glucose.

* Self-reported

^†^ Undiagnosed diabetes is defined as A1C ≥6.5% and/or FPG ≥126 mg/dL.

^‡^ Prediabetes is defined as A1C 5.7%–<6.5% or FPG 100–<126 mg/dL.

^§^ Normal glucose is defined as A1C <5.7% and FPG <100 mg/dL.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

TABLE 4.

Prevalence of Diagnosed Diabetes Among Adults Age ≥65 Years, by Race/Ethnicity, U.S., 2022–2023

RACE/ETHNICITY | PERCENT (STANDARD ERROR)
Non-Hispanic White | 16.9 (0.4)
Non-Hispanic Black | 30.1 (1.3)
Hispanic | 31.4 (1.5)
Mexican American* | 33.1 (2.2)
Other Hispanic* | 29.8 (2.1)
Non-Hispanic Asian | 29.6 (2.2)

Diagnosed diabetes is self-reported.

* Mexican American and Other Hispanic are subsets of the Hispanic category.

SOURCE: National Health Interview Surveys 2022–2023

TABLE 5.

Race/Ethnicity Distribution Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2022–2023

RACE/ETHNICITY | PERCENT (STANDARD ERROR)
RACE/ETHNICITY | Diabetes | No Diabetes
Non-Hispanic White | 63.5 (1.2) | 78.9 (0.7)
Non-Hispanic Black | 14.3 (0.8) | 8.4 (0.4)
Hispanic | 14.8 (1.0) | 8.2 (0.5)
Mexican American* | 51.8 (3.7) | 48.0 (2.9)
Other Hispanic* | 48.2 (3.7) | 52.0 (2.9)
Non-Hispanic Asian | 7.4 (0.8) | 4.5 (0.3)

Diagnosed diabetes is self-reported.

* Mexican American and Other Hispanic are subsets of the Hispanic category.

SOURCE: National Health Interview Surveys 2022–2023

TABLE 6.

Race/Ethnicity Distribution of Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023

RACE/ETHNICITY | PERCENT (STANDARD ERROR)
RACE/ETHNICITY | Age (Years)
RACE/ETHNICITY | 60–69 | 70–79 | ≥80
Non-Hispanic White | 60.0 (1.6) | 64.0 (1.7) | 67.4 (2.3)
Non-Hispanic Black | 16.9 (1.1) | 13.9 (1.1) | 11.3 (1.4)
Hispanic | 16.5 (1.3) | 15.1 (1.4) | 12.0 (1.6)
Mexican American* | 55.3 (4.0) | 53.5 (4.8) | 47.4 (7.2)
Other Hispanic* | 44.7 (4.0) | 46.5 (4.8) | 52.6 (7.2)
Non-Hispanic Asian | 6.6 (0.9) | 7.0 (0.9) | 9.3 (1.7)

Diagnosed diabetes is self-reported.

* Mexican American and Other Hispanic are subsets of the Hispanic category.

SOURCE: National Health Interview Surveys 2022–2023

TABLE 7.

Blood Pressure and LDL Cholesterol Levels in Adults Age ≥65 Years With Diabetes, U.S., 2017–2023

| PERCENT (STANDARD ERROR)
Blood Pressure (mmHg)
Hypertension, ≥130/80 mmHg, or self-report of current use of antihypertensive medications* | 87.6 (1.3)
Systolic
Mean (SE, mmHg) | 132.2 (0.6)
<130 | 48.3 (1.9)
130–139 | 18.4 (1.6)
140–159 | 24.3 (2.1)
≥160 | 9.1 (1.1)
Diastolic
Mean (SE, mmHg) | 70.2 (0.5)
<70 | 53.2 (2.1)
70–79 | 28.8 (2.1)
80–89 | 12.9 (1.6)
≥90 | 5.0 (1.1)
LDL Cholesterol (mg/dL)
Mean (SE, mg/dL) | 83.1 (1.8)
<55 | 15.8 (2.5)
55–69 | 20.7 (2.7)
70–99 | 40.3 (3.4)
100–129 | 14.7 (2.6)
130–159 | 5.1 (1.0)
≥160 | 3.4 (1.1)^1^

Diagnosed diabetes is self-reported. A conversion formula for LDL cholesterol values is available in the Conversions section. LDL, low-density lipoprotein; SE, standard error.

* Self-report of hypertension is defined by being told by a doctor or health professional that you have hypertension, also known as high blood pressure. Current use of medication for high blood pressure is self-reported.

^1^ Relative standard error 30%–40%

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

TABLE 8.

Medication Use Among Adults Age ≥65 Years With Diabetes, by Age, U.S., 2017–2020

MEDICATION | PERCENT (STANDARD ERROR)
MEDICATION | Age (Years)
MEDICATION | ≥65 | 60–69 | 70–79 | ≥80
Metformin | 58.5 (2.8) | 64.0 (4.8) | 62.6 (3.5) | 41.8 (4.9)
Sulfonylureas | 30.1 (2.8) | 28.9 (3.4) | 31.8 (3.5) | 27.8 (5.8)
SGLT2 inhibitors | 3.7 (1.1) | 6.8 (2.5)^1^ | 4.9 (1.8)^1^ | ^3^
GLP-1 receptor agonists | 4.0 (1.2) | 3.1 (0.8) | 4.0 (1.9)^2^ | ^3^
Thiazolidinediones | 5.3 (1.6) | 4.6 (2.1)^2^ | 5.4 (1.4) | 5.1 (2.4)^2^
Insulin | 27.7 (1.8) | 24.0 (2.4) | 25.0 (3.5) | 29.9 (6.3)
Other glucose-lowering medications* | 14.8 (2.5) | 16.6 (2.6) | 16.2 (3.4) | 11.8 (4.3)^1^
Statins | 67.6 (2.8) | 72.6 (3.8) | 66.2 (3.2) | 61.4 (3.6)
ACEi/ARBs^†^ | 66.3 (3.1) | 62.7 (3.5) | 69.5 (4.1) | 63.5 (5.9)

Diagnosed diabetes is self-reported. ACEi, angiotensin-converting enzyme inhibitor; ARB, angiotensin II receptor blocker; GLP-1, glucagon-like peptide-1; SGLT2, sodium-glucose cotransporter-2.

* Other glucose-lowering medications include alpha-glucosidase inhibitors, meglitinides, antidiabetic combinations, dipeptidyl peptidase-4 inhibitors, and amylin analogs.

^†^ ACEi/ARBs include ACE inhibitors with thiazides, angiotensin II inhibitors with thiazides, ACE inhibitors with calcium channel blocking agents, and angiotensin II inhibitors with calcium channel blockers.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–2020

TABLE 9.

Current Smoking Among Older Adults Age ≥60 Years, by Diabetes Status and Age, U.S., 2017–2023

AGE (YEARS) | PERCENT (STANDARD ERROR)
AGE (YEARS) | Diabetes | No Diabetes
≥65 | 8.3 (1.2) | 8.5 (0.7)
60–69 | 15.9 (1.6) | 14.5 (1.1)
70–79 | 7.6 (1.3) | 9.1 (0.9)
≥80 | 2.1 (1.0)^1^ | 3.4 (0.7)

Data are self-reported.

^1^ Relative standard error >40%–50%

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

TABLE 10.

Geriatric Comorbidities Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023

COMORBIDITY | PERCENT (STANDARD ERROR)
COMORBIDITY | Diabetes | No Diabetes
Urinary incontinence* | 35.3 (1.8) | 28.8 (1.3)
Depression^†^ | 12.2 (1.3) | 6.2 (0.6)

Data are self-reported.

* Urinary incontinence is defined as reporting urinary leakage occurring a few times a week or every day and/or night.

^†^ Depression is defined as Patient Health Questionnaire (PHQ-9) score ≥10.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

TABLE 11.

Geriatric Comorbidities Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2017–2023

COMORBIDITY | PERCENT (STANDARD ERROR)
COMORBIDITY | Age (Years)
COMORBIDITY | ≥65 | 60–69 | 70–79 | ≥80
Urinary incontinence* | 35.3 (1.8) | 25.8 (2.9) | 34.2 (2.5) | 45.8 (2.7)
Depression^†^ | 12.2 (1.3) | 14.3 (2.7) | 13.0 (1.8) | 10.0 (2.4)

Data are self-reported.

* Urinary incontinence is defined as reporting urinary leakage occurring a few times a week or every day and/or night.

^†^ Depression is defined as Patient Health Questionnaire (PHQ-9) score ≥10.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

TABLE 12.

Chronic Pain in Past 3 Months Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2023

| PERCENT (STANDARD ERROR)
| Diabetes | No Diabetes
Any pain* | 45.5 (1.4) | 33.5 (0.6)
Back pain^†^ | 42.4 (1.5) | 33.5 (0.7)
Hand pain^†^ | 36.4 (1.4) | 27.6 (0.7)
Hip pain^†^ | 52.6 (1.5) | 40.1 (0.8)
Migraine/headache^†^ | 9.8 (0.9) | 7.8 (0.4)
Abdominal pain^†^ | 9.2 (0.8) | 5.8 (0.4)
Toothache/jaw pain^†^ | 5.3 (0.7) | 4.1 (0.3)

Data are self-reported.

* Any pain is defined as reporting pain in the past 3 months on most days or every day.

^†^ Pain by location is among those reporting pain some days, most days, or every day in the past 3 months. People reporting “a lot” or “somewhere in between a little and a lot” of pain were determined to have pain at that location.

SOURCE: National Health Interview Survey 2023

TABLE 13.

Disability and Functional Limitations of Adults Age ≥65 Years, by Diabetes Status, U.S. 2022–2023

| PERCENT (STANDARD ERROR)
| Diabetes | No Diabetes
Disability Index* | 28.3 (0.9) | 15.8 (0.4)
Difficulty ≥1 with functional limitations^†^ | 40.5 (1.0) | 21.2 (0.4)
Difficulty walking or climbing steps | 21.8 (0.8) | 10.4 (0.3)
Difficulty walking 100 yards | 9.5 (0.7) | 3.6 (0.2)
Difficulty walking 1/3 mile | 17.4 (0.9) | 9.3 (0.3)
Difficulty walking steps | 8.2 (0.7) | 4.0 (0.2)
Difficulty with self-care | 5.1 (0.5) | 2.4 (0.2)
Difficulty raising 2L bottle water/soda from waist to eye level | 5.7 (0.5) | 2.9 (0.2)
Difficulty using hands and fingers | 5.5 (0.4) | 3.3 (0.2)

Diagnosed diabetes is self-reported.

* Disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have any disability.

^†^ Functional limitation: Limitation is defined as a report of the activity having a lot of difficulty or cannot do at all (vs. no difficulty or some difficulty). Difficulty with one or more physical limitations listed in the table.

SOURCE: National Health Interview Surveys 2022–2023

TABLE 14.

Disability and Functional Limitations of Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023

| PERCENT (STANDARD ERROR)
| Age (Years)
| ≥65 | 60–69 | 70–79 | ≥80
Disability Index* | 28.3 (0.9) | 23.6 (1.1) | 26.1 (1.3) | 43.0 (2.3)
Difficulty ≥1 functional limitations^†^ | 40.5 (1.0) | 30.9 (1.2) | 39.7 (1.5) | 62.0 (2.5)
Difficulty walking or climbing steps | 21.8 (0.8) | 17.9 (1.0) | 20.1 (1.2) | 34.1 (2.2)
Difficulty walking 100 yards | 9.5 (0.7) | 7.3 (0.8) | 8.9 (1.0) | 16.3 (2.4)
Difficulty walking 1/3 mile | 17.4 (0.9) | 13.5 (1.1) | 17.7 (1.3) | 27.8 (2.8)
Difficulty walking steps | 8.2 (0.7) | 7.5 (0.8) | 8.0 (0.9) | 13.6 (2.4)
Difficulty with self-care | 5.1 (0.5) | 2.9 (0.5) | 4.8 (0.7) | 8.9 (1.5)
Difficulty raising 2L bottle water/soda from waist to eye level | 5.7 (0.5) | 4.4 (0.6) | 4.8 (0.6) | 10.3 (1.5)
Difficulty using hands and fingers | 5.5 (0.4) | 4.7 (0.6) | 5.3 (0.6) | 8.4 (1.2)

Diagnosed diabetes is self-reported.

* Disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have any disability.

^†^ Functional limitation: Limitation is defined as a report of the activity having a lot of difficulty or cannot do at all (vs. no difficulty or some difficulty). Difficulty with one or more physical limitations listed in the table.

SOURCE: National Health Interview Surveys 2022–2023

## Appendices

APPENDIX TABLE A1.

Trends in the Prevalence of Diagnosed Diabetes Among Adults Age ≥60 Years, by Age, U.S., 2000–2023

YEAR | PERCENT (STANDARD ERROR)
YEAR | Age (Years)
YEAR | ≥65 | 60–69 | 70–79 | ≥80
2000 | 14.6 (0.5) | 14.0 (0.7) | 15.8 (0.7) | 11.2 (0.9)
2001 | 15.2 (0.5) | 15.2 (0.7) | 16.6 (0.8) | 12.2 (0.9)
2002 | 16.0 (0.5) | 15.6 (0.7) | 17.1 (0.8) | 12.5 (0.9)
2003 | 16.6 (0.6) | 15.5 (0.7) | 16.9 (0.8) | 14.2 (1.1)
2004 | 17.3 (0.6) | 16.2 (0.7) | 18.8 (0.9) | 13.8 (0.9)
2005 | 17.0 (0.5) | 16.4 (0.7) | 18.4 (0.8) | 14.2 (0.9)
2006 | 18.0 (0.7) | 17.1 (0.9) | 19.8 (1.1) | 16.2 (1.2)
2007 | 18.7 (0.7) | 16.9 (0.8) | 20.0 (1.1) | 15.7 (1.3)
2008 | 18.5 (0.7) | 18.0 (0.9) | 19.6 (1.1) | 16.1 (1.2)
2009 | 19.5 (0.7) | 17.9 (0.8) | 21.1 (1.1) | 17.3 (1.2)
2010 | 21.4 (0.7) | 19.2 (0.8) | 24.3 (1.1) | 18.4 (1.1)
2011 | 20.6 (0.6) | 18.9 (0.7) | 22.3 (0.9) | 17.4 (1.1)
2012 | 20.0 (0.6) | 19.0 (0.7) | 21.4 (1.0) | 17.9 (1.1)
2013 | 21.0 (0.6) | 18.8 (0.7) | 21.6 (0.9) | 21.0 (1.2)
2014 | 20.5 (0.6) | 18.0 (0.6) | 22.5 (0.9) | 17.4 (1.1)
2015 | 21.7 (0.6) | 20.4 (0.8) | 22.3 (0.9) | 20.1 (1.2)
2016 | 20.6 (0.6) | 18.8 (0.7) | 22.0 (0.9) | 17.3 (0.9)
2017 | 19.1 (0.6) | 18.1 (0.8) | 20.7 (0.9) | 17.1 (1.1)
2018 | 21.5 (0.6) | 18.3 (0.7) | 23.3 (1.0) | 19.9 (1.2)
2019 | 20.2 (0.5) | 17.2 (0.6) | 22.4 (0.8) | 19.0 (1.0)
2020 | 20.9 (0.6) | 17.4 (0.6) | 21.8 (0.8) | 20.2 (1.1)
2021 | 19.4 (0.5) | 17.1 (0.6) | 21.0 (0.7) | 18.4 (1.1)
2022 | 20.1 (0.5) | 17.2 (0.6) | 21.8 (0.8) | 19.4 (1.1)
2023 | 20.5 (0.5) | 18.1 (0.6) | 21.7 (0.7) | 18.8 (1.0)

Diagnosed diabetes is self-reported.

SOURCE: National Health Interview Surveys 2000–2023

APPENDIX TABLE A2.

Trends in the Number of Adults Age ≥60 Years With Diagnosed Diabetes, by Age, U.S., 2000–2023

YEAR | NUMBER (IN MILLIONS)*
YEAR | Age (Years)
YEAR | ≥65 | 60–69 | 70–79 | ≥80
2000 | 4.76 | 2.76 | 2.54 | 0.84
2001 | 5.00 | 3.03 | 2.61 | 0.96
2002 | 5.28 | 3.18 | 2.69 | 1.00
2003 | 5.67 | 3.37 | 2.69 | 1.23
2004 | 5.99 | 3.76 | 2.89 | 1.23
2005 | 5.95 | 3.80 | 2.89 | 1.33
2006 | 6.43 | 4.12 | 3.02 | 1.54
2007 | 6.75 | 4.47 | 3.11 | 1.50
2008 | 6.86 | 4.80 | 3.09 | 1.62
2009 | 7.37 | 4.97 | 3.43 | 1.76
2010 | 8.28 | 5.65 | 3.99 | 1.86
2011 | 8.18 | 5.83 | 3.72 | 1.82
2012 | 8.37 | 6.15 | 3.69 | 1.92
2013 | 9.09 | 6.18 | 3.96 | 2.22
2014 | 9.22 | 6.16 | 4.33 | 1.83
2015 | 10.1 | 6.99 | 4.41 | 2.25
2016 | 9.88 | 6.89 | 4.43 | 1.91
2017 | 9.44 | 6.73 | 4.50 | 1.98
2018 | 11.1 | 7.07 | 5.22 | 2.32
2019 | 10.6 | 6.62 | 5.26 | 2.31
2020 | 11.3 | 6.68 | 5.37 | 2.46
2021 | 10.8 | 6.68 | 5.43 | 2.29
2022 | 11.3 | 6.85 | 5.62 | 2.38
2023 | 11.9 | 7.17 | 5.80 | 2.43

Diagnosed diabetes is self-reported.

* NHIS weighted estimates

SOURCE: National Health Interview Surveys (NHIS) 2000–2023

APPENDIX TABLE A3.

Duration of Diabetes Among Adults Age ≥60 Years, by Age, U.S., 2022–2023

DIABETES DURATION (YEARS) | AGE (YEARS)
DIABETES DURATION (YEARS) | 60–69 | 70–79 | ≥80
Mean (standard error) | 14.2 (0.3) | 17.4 (0.4) | 22.3 (0.7)
| Percent (Standard Error)
<5 | 20.5 (1.1) | 14.5 (1.0) | 8.5 (1.3)
5–<10 | 20.2 (1.1) | 14.7 (1.0) | 12.9 (1.5)
≥10 | 59.3 (1.4) | 70.7 (1.3) | 78.6 (1.8)

Data are self-reported.

SOURCE: National Health Interview Surveys 2022–2023

APPENDIX TABLE A4.

Body Mass Index Distribution Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023

BODY MASS INDEX (kg/m^2^)* | DIABETES | NO DIABETES
Mean (standard error) | 31.6 (0.3) | 28.7 (0.1)
| Percent (Standard Error)
Underweight | ^1^ | 0.9 (0.2)
Healthy weight | 11.3 (1.4) | 25.4 (1.1)
Overweight, not obese | 34.4 (2.0) | 37.2 (1.4)
Obese | 53.9 (2.3) | 36.5 (1.5)

Diagnosed diabetes is self-reported.

* Body mass index (BMI), based on weight and height measured in a standard physical examination, is defined as: underweight, <18.5 kg/m^2^; healthy weight, 18.5–<25 kg/m^2^; overweight, 25–<30 kg/m^2^; obese, ≥30 kg/m^2^, except for non-Hispanic Asian adults where categories are defined as underweight, <18.5 kg/m^2^; healthy weight, 18.5–22.9 kg/m^2^; overweight, 23.0–27.4 kg/m^2^; obese, ≥27.5 kg/m^2^.

^1^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

APPENDIX TABLE A5.

Body Mass Index Distribution Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023

BODY MASS INDEX (kg/m^2^)* | AGE (YEARS)
BODY MASS INDEX (kg/m^2^)* | ≥65 | 60–69 | 70–79 | ≥80
Mean (SE) | 29.8 (0.1) | 30.9 (0.2) | 29.8 (0.2) | 28.3 (0.2)
| Percent (Standard Error)
Underweight | 0.6 (0.2) | 0.5 (0.2)^1^ | 0.7 (0.2)^1^ | ^2^
Healthy weight | 16.7 (0.8) | 11.4 (0.9) | 15.1 (1.0) | 25.4 (1.9)
Overweight, not obese | 35.8 (1.0) | 32.3 (1.2) | 36.6 (1.3) | 37.9 (2.2)
Obese | 46.9 (1.0) | 55.8 (1.3) | 47.5 (1.5) | 35.8 (2.1)

Diagnosed diabetes is self-reported. SE, standard error.

* Body mass index (BMI), based on self-reported weight and height, is defined as: underweight, <18.5 kg/m^2^; healthy weight, 18.5–<25 kg/m^2^; overweight, 25–<30 kg/m^2^; obese, ≥30 kg/m^2^, except for non-Hispanic Asian adults where categories are defined as underweight, <18.5 kg/m^2^; healthy weight, 18.5–22.9 kg/m^2^; overweight, 23.0–27.4 kg/m^2^; obese, ≥27.5 kg/m^2^.

^1^ Relative standard error >30%–40%

^2^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2022–2023

APPENDIX TABLE A6.

Cardiovascular Complications Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023

COMPLICATION | PERCENT (STANDARD ERROR)
COMPLICATION | Diabetes | No Diabetes
Congestive heart failure | 14.6 (1.2) | 5.6 (0.4)
Coronary heart disease | 20.0 (1.8) | 9.6 (0.7)
Heart attack | 14.8 (1.4) | 7.3 (0.7)
Any heart condition with angina* | 8.0 (1.2) | 2.9 (0.3)
Any heart condition without angina* | 22.2 (1.5) | 12.4 (0.9)
Angina | 9.6 (1.3) | 3.7 (0.4)
Stroke | 15.0 (1.6) | 8.2 (0.7)

Data are self-reported.

* Any heart condition includes congestive heart failure, coronary heart disease, or heart attack.

SOURCE: National Health and Nutrition Examination Surveys 2017–2023

APPENDIX TABLE A7.

Cardiovascular Complications Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023

COMPLICATION | PERCENT (STANDARD ERROR)
COMPLICATION | Age (Years)
COMPLICATION | ≥65 | 60–69 | 70–79 | ≥80
Coronary heart disease | 23.9 (0.8) | 17.1 (1.0) | 23.1 (1.1) | 33.0 (2.0)
Angina | 6.9 (0.5) | 5.5 (0.6) | 6.8 (0.7) | 9.1 (1.2)
Heart attack | 14.3 (0.7) | 11.2 (0.8) | 13.8 (0.9) | 19.6 (1.7)
Stroke | 12.1 (0.7) | 8.7 (0.8) | 12.4 (1.0) | 15.4 (1.6)

Data are self-reported.

SOURCE: National Health Interview Surveys 2022–2023

APPENDIX TABLE A8.

Microvascular Complications Among Adults Age ≥65 Years, by Diabetes Status, U.S., 2017–2023

COMPLICATION | PERCENT (STANDARD ERROR)
COMPLICATION | Diabetes | No Diabetes
Retinopathy* | 17.9 (2.1) | NA
Moderately elevated albuminuria^†^ | 28.4 (2.9) | 12.4 (1.1)
eGFR, <60 mL/min per 1.73 m^2 ‡^ | 30.9 (2.8) | 19.1 (1.0)

Diagnosed diabetes is self-reported. A conversion formula for albumin-to-creatinine ratios is available in the Conversions section. NA, not applicable.

* Retinopathy is self-reported and only asked among those with diagnosed diabetes in the NHANES 2017–2020; retinopathy was not included in the 2021–2023 survey cycles.

^†^ Moderately elevated albuminuria is defined as albumin-to-creatinine ratio 30–300 mg/g.

^‡^ Estimated glomerular filtration rate (eGRF) was determined using the CKD-EPI Creatinine Equation 2021.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2017–2023

APPENDIX TABLE A9.

Vision Complications Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2022–2023

COMPLICATION | PERCENT (STANDARD ERROR)
COMPLICATION | Age (Years)
COMPLICATION | ≥65 | 60–69 | 70–79 | ≥80
Trouble seeing* | 28.8 (0.8) | 30.5 (1.2) | 28.5 (1.3) | 31.8 (1.9)
Blindness^†^ | 1.6 (0.5)^1^ | 1.3 (0.6)^2^ | 1.6 (0.7)^2^ | ^3^

Data are self-reported.

* Trouble seeing includes self-reporting some difficulty, a lot of difficulty, or cannot do at all with respect to seeing even when wearing glasses or contact lenses.

^†^ Blindness includes self-reporting cannot do at all with respect to seeing even when wearing glasses or contact lenses among those who reported trouble seeing.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2022–2023

APPENDIX TABLE A10.

Chronic Pain in Past 3 Months Among Adults Age ≥60 Years With Diabetes, by Age, U.S., 2023

CHRONIC PAIN | PERCENT (STANDARD ERROR)
CHRONIC PAIN | Age (Years)
CHRONIC PAIN | ≥65 | 60–69 | 70–79 | ≥80
Any pain* | 45.5 (1.4) | 45.0 (1.8) | 45.4 (2.0) | 47.0 (2.9)
Back pain^†^ | 42.4 (1.5) | 39.3 (2.0) | 46.4 (2.2) | 41.4 (3.1)
Hand pain^†^ | 36.4 (1.4) | 38.4 (2.1) | 38.2 (2.0) | 34.6 (3.1)
Hip pain^†^ | 52.6 (1.5) | 54.9 (2.2) | 50.2 (2.0) | 55.2 (3.3)
Migraine/headache^†^ | 9.8 (0.9) | 15.4 (1.6) | 8.9 (1.2) | 6.5 (1.5)
Abdominal pain^†^ | 9.2 (0.8) | 11.4 (1.4) | 8.7 (1.2) | 9.8 (2.0)
Toothache/jaw pain^†^ | 5.3 (0.7) | 8.1 (1.2) | 4.6 (0.8) | 3.1 (1.1)^1^

Data are self-reported.

* Any pain is defined as reporting pain in the past 3 months on most days or every day.

^†^ Pain by location is among those reporting pain some days, most days, or every day in the past 3 months. People reporting “a lot” or “somewhere in between a little and a lot” of pain were determined to have pain at that location.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Survey 2023