# Liver and Gallbladder Disease in Persons With Diabetes

## Summary

The associations between diabetes and common chronic diseases of the liver and gallbladder, including metabolic dysfunction-associated steatotic liver disease (MASLD), viral hepatitis, cirrhosis, and gallstone disease, are changing over time. We report new analyses on the relationship of these conditions nationally using the National Health and Nutrition Examination Survey (NHANES), Centers for Medicare and Medicaid Services Medicare and Medicaid data, and the Scientific Registry of Transplant Recipients. This article provides a comprehensive and contemporary review of the current state of diabetes as it relates to liver and gallbladder disease in the United States.

In a nationally representative sample of the U.S. population in which diabetes was defined based on diagnosis, glycated hemoglobin (A1C), and fasting plasma glucose, the prevalence of MASLD assessed by transient elastography was greater among persons with diagnosed diabetes (55.7%, 95% confidence interval [CI] 52.2%–59.1%), undiagnosed diabetes (59.2%, 95% CI 52.9%–65.2%), and prediabetes (29.1%, 95% CI 27.0%–31.3%) compared to those with normal glycemia (15.5%, 95% CI 11.3%–21.0%). The MASLD prevalence among persons with diagnosed and undiagnosed diabetes was over twice as high as the general population MASLD prevalence (25.5%, 95% CI 24.4%–26.7%). The proportion of individuals with liver elastography-detected MASLD in the NHANES was much higher than documented MASLD diagnoses derived from claims data, which shows that most people with MASLD are likely undiagnosed. Diabetes and insulin resistance are thought to be closely linked to the development and progression of MASLD, which comprises the liver manifestation of a broader multisystem condition with an underlying etiology of insulin resistance that also includes obesity, diabetes, hyperlipidemia, and hypertension. As the obesity epidemic persists and the diagnosis and treatment of hepatitis B and C have improved, obesity-related liver disease accounts for a growing share of liver disease in the United States. As a result, diabetes is an increasingly important comorbidity requiring consideration and comanagement.

## Introduction

With the increasing prevalence of obesity and improved treatment of viral hepatitis, the epidemiology of liver disease is changing, leading to an increasing association of liver disease with other obesity-related conditions, such as type 2 diabetes. In this article, we report new analyses of nationally representative data to describe the relationship between diabetes and major chronic liver diseases and gallstone disease. In addition, reports and meta-analyses from the medical literature are used to characterize the epidemiology of diabetes and liver and gallbladder disease.

This article provides a comprehensive and contemporary review of the current state of diabetes as it relates to liver and gallbladder disease in the United States and updates the Diabetes in America, 3rd edition, chapter Liver and Gallbladder Disease in Diabetes (1). The article does not address all liver diseases or chronic liver disease in general. The discussion of metabolic dysfunction-associated steatotic liver disease (MASLD), which recently replaced the term nonalcoholic fatty liver disease (NAFLD) to identify steatotic liver disease (SLD) in the presence of at least one cardiometabolic risk factor associated with insulin resistance (e.g., obesity, diabetes, atherogenic dyslipidemia, or hypertension) without other identifiable causes of steatosis, does not include metabolic dysfunction and alcohol-associated steatotic liver disease (MetALD). MetALD is a recently renamed separate category outside of MASLD in which alcohol intake is greater than that allowed for MASLD but less than that attributed to alcohol-associated liver disease. Rather, the authors examine the overlap of diabetes with a few significant and relatively common liver and gallbladder diseases for which national data are available; these diseases include MASLD, chronic hepatitis C virus (HCV) and hepatitis B virus (HBV) infections, and cirrhosis. The significance of diabetes in liver transplantation is also examined. Lastly, the relationship of diabetes with gallstones and cholecystectomy is described.

## Sources and Limitations of National Data on Liver and Gallbladder Disease and Diabetes

### National Health and Nutrition Examination Surveys

The National Health and Nutrition Examination Surveys (NHANES) are nationally representative surveys conducted in the United States by the National Center for Health Statistics of the Centers for Disease Control and Prevention to assess the health and nutritional status of the general U.S. population (2). The NHANES consists of interviews, physical examinations, and laboratory tests and procedures. The NHANES III (1988–1994) and NHANES 2011–March 2020 and August 2021–August 2023 were used to generate new data for the U.S. population on the relationships of diabetes and prediabetes with MASLD, HCV, HBV, and gallstone disease. The NHANES provides national data on diagnosed and undiagnosed diabetes. Participants are asked about a health care provider diagnosis of diabetes and have measurements of serum glycated hemoglobin (A1C) and fasting plasma glucose. Diabetes is defined in the NHANES as diagnosed diabetes (self-reported doctor or health professional diagnosis) and, among persons without a diagnosis, as undiagnosed diabetes (A1C ≥6.5% [≥48 mmol/mol] or fasting glucose ≥126 mg/dL [≥6.99 mmol/L]), prediabetes (A1C 5.7%–6.4% [39–46 mmol/mol] or fasting glucose 100–125 mg/dL [5.55–6.94 mmol/L]), or normal glycemia levels (A1C <5.7% and fasting glucose <100 mg/dL).

In the NHANES 2017–March 2020 and August 2021–August 2023, transient elastography was used to measure controlled attenuation parameter (CAP) and liver stiffness, biomarkers of hepatic steatosis and fibrosis, providing the only U.S. nationally representative transient elastography biomarker data (3). In the NHANES III, abdominal ultrasonography was performed on adults age 20–74 years who underwent an examination at a mobile examination center, providing the only national data on subclinical gallstone disease. In the NHANES 2017–March 2020 and August 2021–August 2023, information was again collected on gallstone disease but was based on self-report, so asymptomatic gallstone disease could not be detected. NHANES serum specimens have been analyzed for markers of HBV (core total antibody [HBcAb] and surface antigen [HBsAg]) and HCV (antibody and, since 1999, ribonucleic acid [RNA]).

A strength of the NHANES is the large sample that is representative of the general U.S. population. A limitation of the NHANES is the cross-sectional design that does not permit determination of temporal relationships between abnormal glucose metabolism and diseases of the liver and gallbladder.

### Centers for Medicare and Medicaid Services Medicare 5% Sample

The Centers for Medicare and Medicaid Services (CMS) created the Medicare 5% sample files to be representative of the entire population of Medicare beneficiaries; they are housed in the CMS Chronic Conditions Data Warehouse (4). Demographic and enrollment data are linked by a unique, unidentifiable beneficiary key to institutional and noninstitutional medical claims files. Medicare claims data from January 1, 2022 through December 31, 2022 for age-eligible beneficiaries were used to generate new data on the relationships of diabetes with MASLD, cirrhosis, liver transplantation, and gallstone disease. Strengths of Medicare data include the large size of the database and coverage of approximately 96% of all U.S. citizens age ≥65 years, permitting generalization to the U.S. older adult population (5). A limitation of this database is that information on diabetes and liver and gallbladder diseases is based on International Classification of Diseases (ICD) code diagnoses that are not verified and may underestimate disease prevalence due to both underdiagnosis and systemic undercoding despite a recognized diagnosis.

### CMS Medicaid Files

The CMS Medicaid files include the entire population of Medicaid beneficiaries and are housed in the Chronic Conditions Data Warehouse (4). Demographic and enrollment data are linked by a unique, unidentifiable beneficiary key to institutional and noninstitutional medical claims files. Medicaid eligibility is based on income below a certain level that varies among states, so Medicaid beneficiaries represent a low-income population. Medicaid claims data from January 1, 2022 through December 31, 2022 for beneficiaries age 20–64 years were used to generate new data on the relationships of diabetes with MASLD, cirrhosis, liver transplantation, and gallstone disease. Strengths of Medicaid data are the large size of the database and inclusion of information on Asians, American Indians/Alaska Natives, and Hawaiians/Pacific Islanders, groups for which data are less commonly available. A limitation of this database is that information on diabetes and liver and gallbladder diseases is based on ICD code diagnoses that are not verified and may underestimate disease prevalence due to both underdiagnosis and systemic undercoding despite a recognized diagnosis. In addition, Medicaid program eligibility varies from state to state, so data may be inconsistent across states.

### Scientific Registry of Transplant Recipients

The Scientific Registry of Transplant Recipients (SRTR) is a national database of transplantation statistics that was founded to support evaluation of the scientific and clinical status of solid organ transplantation, including liver (6). Data are collected by the Organ Procurement and Transplantation Network (OPTN) from hospitals and organ procurement organizations throughout the United States. The SRTR is administered by the Chronic Disease Research Group of the Hennepin Healthcare Research Institute, with oversight and funding from the Health Resources and Services Administration. The SRTR Standard Analysis File includes data on all persons in the U.S. population listed as candidates for liver transplantation. Information on diabetes has been included in the Standard Analysis File since 1994. SRTR 2014–2023 data were used to examine the relationship of liver transplantation and diabetes in the U.S. population. Limitations of this database are that the quality of the data is unverified and diabetes diagnosis is self-reported.

### Statistical Methods

For new analyses of the national databases described above, we calculated age-standardized prevalences of liver and gallbladder diseases by diabetes status in the overall population and among groups stratified by age, sex, race/ethnicity, and for claims data, region. All results from national surveys are statistically weighted to produce estimates that are nationally representative of the noninstitutionalized U.S. population. In cases where the sample size is small and the results may be imprecise, the relative standard error (RSE = [standard error/estimate]*100) is provided in tables. If RSEs are >50%, the results are not shown. We also calculated odds ratios (OR) for liver and gallbladder diseases, comparing diabetes groups to the normal glycemia group.

## Metabolic Dysfunction-Associated Steatotic Liver Disease (MASLD)

### Steatotic Liver Disease (SLD): Description and Diagnosis

SLD is a chronic liver disease and has been an increasingly significant public health burden over the past two decades (7,8,9,10). Chronic liver disease and cirrhosis lead to increased morbidity and ranked as the 9th or 10th leading cause of death in the United States between 2021 and 2023 (11,12). SLD is a leading cause of chronic liver disease in the United States and can progress to severe fibrosis and cirrhosis with increased risk of liver-related complications and death (13,14,15,16). The burden of SLD has grown due to the worsening epidemics of obesity and diabetes in the absence of optimal care of the growing number of persons affected by these conditions.

In order to better address the increasing SLD burden, a new nomenclature and definitions were recently adopted following a multisociety consensus process (7,8). SLD is an overarching term that identifies individuals with hepatic steatosis. SLD is defined as the presence of macrovesicular steatosis in ≥5% of hepatocytes and is identified by imaging (abdominal ultrasound, transient elastography-assessed CAP, or magnetic resonance imaging–proton density fat fraction [MRI-PDFF]) or by histology (17). SLD encompasses MASLD, which is a replacement term for NAFLD. This change reflects the metabolic basis of MASLD that is considered to be part of a broader multisystem condition with an underlying etiology of insulin resistance that also includes obesity, diabetes, hyperlipidemia, and hypertension. MASLD is defined as the presence of hepatic steatosis, diagnosed histologically or by imaging, in conjunction with at least one of five cardiometabolic risk factors (overweight or obesity, prediabetes or diabetes, elevated blood pressure, high triglycerides, and low high-density lipoprotein [HDL] cholesterol) and no other discernable cause (7). The MASLD requirement of one or more cardiometabolic risk factor raised questions as to whether new evidence on clinical profile and outcomes would need to be generated for MASLD. However, a 2024 report using both tertiary care and U.S. national population-based data found that the vast majority of NAFLD patients fulfilled criteria for MASLD, and noninvasive tests performed similarly in NAFLD and MASLD patients, while a slightly higher mortality risk for MASLD was likely because of the requirement for one or more cardiometabolic risk factor (18). These results provide evidence that data generated in the past three decades for NAFLD can be used interchangeably for MASLD. In this article, we use the newest terminology for clarity (or in describing reports, we use the terminology in use at the time of the report).

SLD also includes a new overlap category that represents individuals with hepatic steatosis from a combination of cardiometabolic risk factors and a spectrum of alcohol consumption (weekly alcohol intake of 140–350 g in women and 210–420 g in men, average daily 20–50 g women, 30–60 g men), called MetALD. SLD encompasses other causes of hepatic steatosis, including alcohol-associated liver disease, drug-induced liver injury, monogenic diseases, and hepatic steatosis from other less common aetiologies. Individuals with hepatic steatosis who consume alcohol in excess of 50 g (women) or 60 g (men) daily, or weekly equivalent, are classified as having alcohol-associated liver disease, since alcohol is likely to be the dominant driver of liver disease in these individuals.

Transient elastography by FibroScan^®^ is a practical, noninvasive tool for identifying elevated liver stiffness as a biomarker for liver fibrosis in the general population and has been widely used for chronic liver disease surveillance over the past decade (19,20). The presence of increased fibrosis marks progression from MASLD, in which excess fat accumulates in the liver, to metabolic dysfunction-associated steatohepatitis (MASH), a state in which inflammation and liver cell damage has developed. MASH is a precursor of cirrhosis, characterized by more extensive scarring and liver dysfunction.

### Prevalence of MASLD in the United States

The prevalence of MASLD and fibrosis is high in the U.S. population. Using liver stiffness and CAP data from transient elastography assessed on 13,538 participants age ≥20 years in the NHANES 2017–March 2020 and August 2021–August 2023, the prevalence of SLD (CAP >300 dB/m) was 28.7% (95% confidence interval [CI] 27.5%–29.8%), and the prevalence of MASLD (CAP >300 dB/m with one or more cardiometabolic risk factors and without excessive alcohol use) was 25.5% (95% CI 24.4%–26.7%) (21). The prevalence of elevated liver stiffness (>8 kPa) was 11.3% (95% CI 10.3%–12.4%) in the overall population and as high as 24.1% (95% CI 21.3%–27.1%) among persons with MASLD (21). Because there are no universally accepted cut points for identifying hepatic steatosis and stiffness in the general population, a CAP cut point of >300 dB/m and liver stiffness cut point of >8 kPa were used, based on the optimized sensitivity and specificity reported in earlier studies (22,23). It should be noted that prevalence may vary if different cut points are used. The prevalence of MASLD was 38.3% in Hispanic persons compared to 30% in non-Hispanic Asian, 23% in non-Hispanic Black, and 31% in non-Hispanic White persons in another report that used a slightly lower CAP cut point of 288 dB/m (24). In multivariable-adjusted analysis, both MASLD and elevated liver stiffness were associated with diabetes, higher body mass index (BMI) and waist-to-hip ratio, and elevated blood pressure and inversely associated with non-Hispanic Black race/ethnicity (21). MASLD was also associated with male sex, non-Hispanic Asian race/ethnicity, prediabetes, higher total cholesterol, lower HDL cholesterol, and a more sedentary lifestyle. Elevated liver stiffness was also associated with SLD, lower total cholesterol, and less education.

New analyses of the cross-sectional, population-based NHANES 2017–March 2020 and August 2021–August 2023 data on diabetes and hepatic steatosis and elevated liver stiffness assessed by transient elastography were conducted for Diabetes in America. MASLD was defined as a CAP >300 dB/m among persons without heavy alcohol intake (<3 drinks/day for men and <2 drinks/day for women), and elevated liver stiffness was defined as >8 kPa, as used in a previous report (21). The age-standardized prevalence of MASLD was higher among adults age ≥20 years with diagnosed diabetes (55.7%, 95% CI 52.2%–59.1%), undiagnosed diabetes (59.2%, 95% CI 52.9%–65.2%), and prediabetes (29.1%, 95% CI 27.0%–31.3%) compared with participants with normal glycemia (15.5%, 95% CI 11.3%–21.0%) (Figure 1, Table 1). The MASLD prevalence among persons with diagnosed and undiagnosed diabetes was over twice as high as the general population MASLD prevalence (25.5%, 95% CI 24.4%–26.7%). A higher MASLD prevalence among persons with diabetes and prediabetes was also seen among age, sex, and race/ethnicity groups. With adjustment for age, sex, and race/ethnicity, the odds ratio for MASLD remained higher for diagnosed diabetes (OR 8.3, 95% CI 6.1–11.2), undiagnosed diabetes (OR 10.4, 95% CI 7.6–14.2), and prediabetes (OR 2.5, 95% CI 2.0–3.1) relative to normal glycemia. In a published multivariable analysis that also adjusted for weight-related (BMI and waist-to-hip ratio), metabolic (total cholesterol, HDL cholesterol, blood pressure, and C-reactive protein), lifestyle (cigarette smoking, physical activity, and sedentary behavior), and socioeconomic (education level) factors, MASLD remained associated with diabetes (OR 2.5, 95% CI 2.0–3.2) and prediabetes (OR 1.5, 95% CI 1.2–1.8) (21,25).

The age-standardized prevalence of elevated liver stiffness was higher among participants with diagnosed diabetes (27.4%, 95% CI 24.2%–30.8%) and undiagnosed diabetes (23.6%, 95% CI 18.4%–29.7%) compared with participants with normal glycemia (7.2%, 95% CI 5.0%–10.1%) (Figure 1, Table 2). The prevalence of elevated liver stiffness among persons with diagnosed and undiagnosed diabetes was over twice as high as the general population prevalence (11.3%, 95% CI 10.3%–12.4%) and similar to the prevalence among persons with MASLD (24.1%, 95% CI 21.3%–27.1%). A higher prevalence of elevated liver stiffness among persons with diabetes was also seen among age, sex, and race/ethnicity groups. With adjustment for age, sex, and race/ethnicity, the odds ratio for elevated liver stiffness remained increased for adults with diagnosed diabetes (OR 7.2, 95% CI 4.7–11.0) and undiagnosed diabetes (OR 6.2, 95% CI 3.8–10.0) and became higher for prediabetes (OR 2.1, 95% CI 1.3–3.3) relative to adults with normal glycemia. In a published multivariable analysis that also adjusted for weight-related (BMI and waist-to-hip ratio), metabolic (SLD, total cholesterol, HDL cholesterol, blood pressure, and C-reactive protein), lifestyle (alcohol use, cigarette smoking, physical activity, and sedentary behavior), and socioeconomic (education level) factors, elevated liver stiffness remained associated with diabetes (OR 2.0, 95% CI 1.5–2.6), but not with prediabetes (OR 1.2, 95% CI 1.0–1.6) (21,25).

MASLD is on the rise among children and adolescents. In a systematic review and meta-analysis of 62 studies (age [years] range, 2–20; median, 3.9–17.5), the prevalence of MASLD in the pediatric population was 13% overall, with a higher prevalence observed in boys than in girls (26). Similar to adults, diabetes and obesity are the most significant risk factors for MASLD in children and adolescents. A detailed discussion of MASLD in children and adolescents with type 1 and type 2 diabetes can be found in the Diabetes in America article Diabetes in Children and Adolescents (27).

New analyses of the cross-sectional, population-based NHANES 2017–March 2020 and August 2021–August 2023 data on diabetes and hepatic steatosis and elevated liver stiffness assessed by transient elastography among adolescents age 12–19 years were conducted for Diabetes in America. SLD was defined as a CAP >250 dB/m and elevated liver stiffness as >6 kPa. There are no universally accepted CAP and liver stiffness cut points for pediatric populations (28). We chose less stringent cut points for adolescents compared with adults, though this may limit comparability to adults. Diabetes and prediabetes were combined due to small numbers of adolescents with diabetes and defined as a self-reported health care provider diagnosis, A1C ≥5.7%, or fasting plasma glucose ≥100 mg/dL. The prevalence of SLD was higher among participants with diabetes/prediabetes (32.3%, 95% CI 27.4%–37.5%) compared with participants with normal glycemia (21.3%, 95% CI 17.2%–26.1%) (Table 3). A higher SLD prevalence among persons with diabetes/prediabetes was also seen among some age, sex, and race/ethnicity groups, but not all groups, likely due to small numbers of participants. With adjustment for age, sex, and race/ethnicity, the odds ratio for SLD remained higher for diabetes/prediabetes relative to normal glycemia (OR 1.7, 95% CI 1.2–2.5). The prevalence of elevated liver stiffness did not differ among participants with diabetes/prediabetes compared with participants with normal glycemia overall or among demographic groups, and the age-sex-race/ethnicity adjusted odds ratio for elevated liver stiffness was not increased for diabetes/prediabetes relative to normal glycemia (Table 3).

New analyses were also conducted among 54.4 million age-eligible Medicare beneficiaries age ≥65 years in 2022. Diabetes was defined by ICD, Tenth Revision, Clinical Modification (ICD-10-CM) codes E10–E11 in any position on a claim. MASLD was defined by ICD-10-CM codes K75.81 or K76.0 in any position on a claim. The prevalence of a MASLD diagnosis was higher among people with diagnosed diabetes (5.3%, 95% CI 5.2%–5.4%) compared with people without a diabetes diagnosis (1.5%, 95% CI 1.5%–1.5%) (Table 4). With adjustment for age, sex, race/ethnicity and region, persons with diabetes had over three and a half times higher odds of MASLD compared to persons without diabetes (OR 3.7, 95% CI 3.6–3.8). Higher MASLD prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

Similarly, new analyses were conducted among 39.6 million Medicaid beneficiaries age 19–64 years in 2022 with diabetes and MASLD defined using the same ICD-10-CM codes as for the Medicare analyses. The prevalence of a MASLD diagnosis was higher among persons with diagnosed diabetes (6.0%, 95% CI 6.0%–6.1%) compared with people without a diabetes diagnosis (1.7%, 95% CI 1.7%–1.7%) (Table 5). With adjustment for age, sex, race/ethnicity and region, persons with diabetes had almost fourfold higher odds of MASLD compared to persons without diabetes (OR 3.8, 95% CI 3.7–3.8). Higher MASLD prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups. The difference in the proportion of individuals with liver elastography-detected MASLD in the NHANES in Table 1 and those with documented diagnoses derived from claims data in Tables 4 and 5 shows that most MASLD is likely undiagnosed or undercoded and, hence, patients may not be able to benefit from emerging drug treatment strategies.

### Mortality and Hepatocellular Carcinoma Risks Associated With MASLD

Diabetes is an important driver of mortality among people with MASLD, with the highest risk of mortality observed among people with MASLD and diabetes, followed by those with prediabetes, and the lowest risk was among those without diabetes (29). Diabetes is also strongly associated with the future risk of hepatocellular carcinoma in persons with MASLD, although there is a stepwise increase in hepatocellular carcinoma risk as the number of metabolic risk factors increases (30).

### MASLD Treatment

Currently, FDA-approved medications are specifically indicated for the treatment of MASH and liver fibrosis (resmetirom and semaglutide), but there are no approved medications for treatment of MASLD alone. Lifestyle modifications are recommended for MASLD based on its weight-related etiology and the efficacy of weight loss in reversing disease progression (31). Anti-obesity medications, including glucagon-like peptide-1 (GLP-1) receptor agonists, are increasingly used to promote weight loss. Increased physical activity is recommended along with a low-calorie healthy diet to achieve weight loss among persons with SLD (32,33,34). The second edition of the Physical Activity Guidelines for Americans recommends at least 150 minutes of moderate-intensity or 75 minutes of vigorous-intensity aerobic physical activity per week (35). For adults with MASLD and diabetes or prediabetes, particularly with overweight or obesity, the American Diabetes Association recommends lifestyle changes that promote weight loss through an individualized structured nutrition plan and physical activity program (36,37). A minimum weight loss of 5%, and preferably 10%, is considered necessary to improve liver histology, with a larger weight reduction required to promote change in fibrosis (36).

Current health disparities in the United States, such as access to healthy food or places to exercise, impose further challenges in implementation of these lifestyle improvements. In the NHANES 2017–March 2020 and August 2021–August 2023, persons with MASLD and with elevated liver stiffness had less education and lower income in age-adjusted analyses, and lower educational attainment remained associated with elevated liver stiffness after accounting for demographic, clinical, and other lifestyle factors (21). In another U.S. population-based report, less favorable social determinants of health scores were associated with increased all-cause and cause-specific mortality among persons with MASLD (38). Early detection of MASLD and targeting lifestyle and other modifiable risk factors among all population groups may slow disease progression toward advanced fibrosis and cirrhosis and decrease the MASLD burden among racial and ethnic minority and other underserved populations.

## Viral Hepatitis (C and B)

The impact of viral hepatitis in the United States has decreased with advances in treatment and prevention. Chronic HCV was once the leading indication for liver transplantation, but in recent years, it has been surpassed by alcohol-associated liver disease, MASH, and hepatocellular carcinoma (see the section Diabetes and Liver Transplantation). While HCV remains a leading cause of liver disease death, in most cases, it is now curable with direct-acting antiviral agents. HBV is preventable through vaccination and treatable with antiviral medications.

### Hepatitis C Virus

An association between HCV and type 2 diabetes was noted beginning shortly after the discovery of HCV in 1989; however, results of early studies were inconsistent (39,40,41,42,43). Several meta-analyses conducted in the past 10 years to further examine the relationship of HCV infection with type 2 diabetes have reported a positive association (Table 6). In one meta-analysis that examined the prevalence of type 2 diabetes among patients with varying HCV infection statuses, diabetes prevalence rose with increasing severity of HCV infection but did not differ in patients with HCV clearance compared with non-HCV controls (44). In two meta-analyses, one of which included exclusively East Asian patients, persons with HCV infection had >50% higher odds of type 2 diabetes compared to those without HCV infection (OR 1.58 for both) (45,46). In another meta-analysis, patients with chronic HCV infection had over twice the odds of type 2 diabetes compared with HCV-negative controls (47). Diabetes prevalence was also higher among patients with HCV infection compared to controls with non-HCV liver disease or with HBV infection, suggesting that HCV infection is associated with type 2 diabetes independent of the severity of the associated liver disease. In addition, patients with type 2 diabetes had almost fourfold higher odds of HCV infection compared with controls without diabetes but did not differ with regard to HBV infection prevalence.

Among population-based studies of the relationship of HCV infection with type 2 diabetes conducted in the past 10 years, findings have been less consistent (Table 6). In over 2.7 million participants in a major health system in the western United States, 0.86% had evidence (diagnosis or positive serology) of HCV infection, and of these, 8.2% were prescribed antiviral treatment (48). A greater proportion of HCV-positive patients had diabetes mellitus compared to HCV-negative patients (unadjusted percentages, 18.7% vs. 8.9%, p<0.0001). In a Swedish nationwide population-based register study, patients with a chronic HCV infection (based on positive serology; 2.3% treated) had more physician-diagnosed and registered diabetes compared with matched general population controls (10.6% vs. 5.5%, p<0.01) (49). In a cohort study of individuals in British Columbia, Canada, those with chronic HCV infection (based on positive serology or treatment) had an increased incidence (per 1,000 person-years) of type 2 diabetes compared with HCV-negative persons (5.85, 95% CI 5.68–6.03 vs. 5.40, 95% CI 5.34–5.46, p<0.001) (50). In a multivariable-adjusted analysis among a matched subset, the risk of type 2 diabetes incidence remained over twice as high among HCV-positive persons. In a Korean national cohort study of persons who underwent health check-ups, the 12-year cumulative incidence of diabetes was 32.9% among diagnosed HCV-infected persons without a prior history of diabetes compared with 18.3% among noninfected persons (51). The adjusted hazard ratio (HR) for diabetes was almost 70% higher, comparing HCV-infected to noninfected persons. Not all population-based studies found a higher prevalence of diabetes among persons with HCV. Among Mexican Americans living in Southern Texas, there was a statistically significant negative association between serology-positive HCV infection and diabetes (OR 0.20, 95% CI 0.05–0.77) after adjusting for sociodemographic and clinical factors (52). Likewise, in a Scottish national population-based register study, compared with HCV-negative matched general population controls, people with serology-positive HCV infection did not have a higher prevalence of diagnosed type 2 diabetes (2.9% vs 2.7%) (53).

Eradication of HCV by direct-acting antiviral agents may impact extrahepatic manifestations, such as diabetes. Achieving a sustained virological response after treatment with direct-acting antiviral agents may reduce insulin resistance and protect against diabetes incidence. However, results from existing reports are inconsistent (54,55,56,57).

New analyses of the cross-sectional, population-based NHANES 2011–March 2020 data on HCV serology and diabetes were conducted for Diabetes in America. The presence of IgG antibody to the virus (anti-HCV) in the blood indicates either past or current infection. A positive blood test for HCV RNA indicates ongoing infection. Among the general adult population, 2.2% were positive for anti-HCV and 1.1% were positive for HCV RNA. The age-standardized prevalence of anti-HCV was similar across categories of glycemia, both overall and by demographic groups (Table 7). The age-sex-race/ethnicity adjusted odds ratios for anti-HCV positivity were not increased for either diabetes or prediabetes relative to normal glycemia. Similarly, the prevalence of HCV RNA positivity was not different across glycemia categories, and the adjusted odds ratios were not higher for diabetes or prediabetes compared to normal glycemia (Table 8). The overall results for anti-HCV and HCV RNA prevalence are summarized in Figure 2. Diabetes and prediabetes remained unassociated with HCV infection in a published multivariate analysis that adjusted for additional factors (58). Reduced HCV burden post-direct-acting antiviral medications may help to explain diminished associations with diabetes compared with pre-2011 literature.

### Hepatitis B Virus

The distribution of chronic HBV infection is highly regional, being endemic throughout much of eastern Asia and parts of Africa and much less prevalent in North America and Western Europe. In the United States, HBV is more common among immigrants from endemic regions. Worldwide, chronic HBV infection may pose a more significant health burden than HCV because the risk of hepatocellular carcinoma is much higher in persons with HBV than those with HCV, and hepatocellular carcinoma remains a leading cause of cancer mortality in much of the world.

Compared to HCV, there is less evidence that HBV increases the risk of diabetes. For example, in a meta-analysis of over 138 million patients, including over 35 million with the metabolic syndrome, chronic HBV infection was associated with lower odds of the metabolic syndrome (OR 0.83, 95% CI 0.71–0.79) and of some of its single components, including increased fasting glucose (59).

New analyses of the cross-sectional, population-based NHANES 2011–March 2020 data on HBV serology and diabetes were conducted for Diabetes in America. For HBV infection, the most commonly used and useful tests for epidemiologic studies are serum hepatitis B core antibody (HBcAb), which indicates exposure to HBV, and hepatitis B surface antigen (HBsAg), which indicates current infection. Among the general adult population age ≥20 years, 6.3% were positive for HBcAb and 0.4% were positive for HBsAg. The age-standardized prevalence of HBcAb was nonsignificantly higher among participants with diabetes (6.8%, 95% CI 5.8%–7.8%) and prediabetes (6.5%, 95% CI 5.5%–7.7%) compared with participants with normal glycemia (5.3%, 95% CI 4.0%–6.9%) (Table 9). A higher HBcAb prevalence among persons with diabetes and prediabetes was not seen among sex, age, and race/ethnicity groups, except among women. Among race/ethnicity groups, HBcAb prevalence was high for non-Hispanic Black adults and highest for non-Hispanic Asian adults. With adjustment for age, sex, and race/ethnicity, the odds ratios for HBcAb were not elevated for adults with diabetes (OR 0.9, 95% CI 0.7–1.1) or prediabetes (OR 1.1, 95% CI 0.9–1.5) relative to those with normal glycemia. The prevalence and odds ratio for the much smaller number of participants positive for HBsAg were not elevated for participants with diabetes or prediabetes relative to those with normal glycemia (Table 10). The overall results for HBcAb and HBsAg prevalence are summarized in Figure 2.

## Diabetes and Cirrhosis

An association of diabetes and liver cirrhosis was established more than 60 years ago (60). However, data on the prevalence of cirrhosis among persons with diabetes are limited and based mainly on MASLD as the etiology (61). In a meta-analysis of seven studies between 2004 and 2017 that included 439 patients with type 2 diabetes and biopsy-confirmed NAFLD, the global prevalence of advanced fibrosis and cirrhosis was 17% (95% CI 7%–35%) (61,62). In the U.S. population among adults with diabetes, the prevalence of transient elastography-defined advanced fibrosis (liver stiffness ≥9.7 kPa) and cirrhosis (liver stiffness ≥13.6 kPa) was 15.4% (95% CI 12.2%–19.0%) and 7.7% (95% CI 4.8%–11.9%), respectively (63). In other reports, the presence of advanced fibrosis in patients with type 2 diabetes was approximately 15%–20% (61).

Conversely, the overall prevalence of diabetes among adults with liver cirrhosis was reported to be 31% (95% CI 28%–34%) in a meta-analysis (Table 11) (64). Diabetes prevalence varied by cirrhosis etiology and was highest with NAFLD (56%) and cryptogenic (51%), HCV (32%), and alcohol-associated (27%) cirrhosis. A lot of cryptogenic cirrhosis may actually be due to NAFLD/MASLD (8). Population-based studies of cirrhosis and diabetes conducted in the past 10 years have reported diabetes prevalence among persons with cirrhosis (Table 11). In a retrospective cohort study of all persons with cirrhosis within a Swedish county in 2011–2018, the prevalence of type 2 diabetes at cirrhosis diagnosis was 29% (65). In a retrospective cohort study of all patients hospitalized for cirrhosis in Queensland, Australia, during 2008–2016, the prevalence of type 2 diabetes at first hospital admission was 19% (66). In both reports, diabetes prevalence varied by cirrhosis type and was highest in NAFLD/MASLD cirrhosis (53% in both). Using the same database from Queensland, Australia, another retrospective cohort study reported a type 2 diabetes incidence of 11% during follow-up from 2008 to 2017 among persons without diabetes at index admission (67). In a cohort of patients with alcoholic or HCV cirrhosis in a Spanish hepatocellular carcinoma surveillance program in 1992–2014, the prevalence of diabetes was 25% (68).

Population-based studies of cirrhosis and diabetes conducted in the past 10 years have reported a higher mortality risk in persons with cirrhosis and a coexisting diabetes diagnosis. In the study of all patients hospitalized for cirrhosis in Queensland, Australia, during 2008–2017, mortality during follow-up was higher among patients with type 2 diabetes compared to patients without type 2 diabetes (56.8% vs. 52.0%, p<0.001) (unadjusted HR 1.36, 95% CI 1.27–1.46) (67). In multivariable analysis, the survival difference between patients with and without type 2 diabetes was explained by variation in comorbidities and sociodemographic characteristics. In a prospective community-based cohort study of Chinese adults in Singapore (n=63,275) with a mean follow-up of 16.9 years, diabetes was associated with an increased risk of cirrhosis mortality overall (HR 2.80, 95% CI 2.04–3.83) and for both viral (HR 2.20, 95% CI 1.18–4.11) and nonviral (HR 3.06, 95% CI 2.13–4.41) hepatitis-related cirrhosis (69).

New analyses of the prevalence of cirrhosis in persons with diabetes were conducted among 54.4 million age-eligible Medicare beneficiaries age ≥65 years in 2022. Diabetes was defined by ICD-10-CM codes E10–E11 in any position on a claim. Cirrhosis was defined by ICD-10-CM codes K70.3, K71.7, or K74.3–K74.6 in any position on a claim. The prevalence of a cirrhosis diagnosis was higher among persons with diagnosed diabetes (2.4%, 95% CI 2.3%–2.4%) compared with people without a diabetes diagnosis (0.6%, 95% CI 0.6%–0.6%) (Table 12). With adjustment for age, sex, race/ethnicity and region, persons with diabetes had fourfold higher odds of cirrhosis compared to persons without diabetes (OR 4.0, 95% CI 3.8–4.1). Higher cirrhosis prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

Similarly, new analyses on cirrhosis were conducted among 39.6 million Medicaid beneficiaries age 19–64 years in 2022, with diabetes and cirrhosis defined using the same ICD-10-CM codes as for the Medicare analyses. The prevalence of a cirrhosis diagnosis was higher among people with diagnosed diabetes (2.0%, 95% CI 2.0%–2.0%) compared with people without a diabetes diagnosis (0.8%, 95% CI 0.7%–0.8%) (Table 13). With adjustment for age, sex, race/ethnicity and region, persons with diabetes had over two and a half times higher odds of cirrhosis compared to persons without diabetes (OR 2.7, 95% CI 2.6–2.7). Higher cirrhosis prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

## Diabetes and Liver Transplantation

The large majority of adult liver transplantation is performed for decompensated cirrhosis and for hepatocellular carcinoma. Most patients with hepatocellular carcinoma also have cirrhosis, but not necessarily advanced enough to trigger the need for transplantation on its own.

For Diabetes in America, 3rd edition, SRTR Standard Analysis File data were analyzed on all patients listed for liver transplantation in the United States in 1994–2013. These results have been updated with a new analysis of the next decade of SRTR data, 2014–2023, for the current article. During 2014–2023, the percentage of patients with a diabetes diagnosis at listing (the date a patient was added to the national liver transplant waiting list) remained relatively stable between 29% and 31% (n=3,036–3,353) (Figure 3). This followed a doubling between 1994 (when diabetes was first recorded as a comorbidity in listed patients) and 2013, from 14% to 28%, which was thought likely due to both an actual increase in diabetes and an increase in its diagnosis (1).

Characteristics of patients with and without a diabetes diagnosis at the time of listing and at transplantation are shown in Table 14. Patients with diabetes were more likely to be older, male, Hispanic, and less educated and to have poorer functional status and a higher BMI than those without diabetes. Interestingly, Model for End-Stage Liver Disease (MELD) scores (a scale used for prioritizing liver transplant candidates in which a higher score indicates a more urgent need within the next 3 months) were lower among patients with diabetes (mean 17.1) than among patients without known diabetes (mean 19.6). At the time of transplant, MELD scores remained lower among those with diabetes. Lower MELD scores among persons with diabetes could result from the high prevalence among persons with diabetes of MASLD (Table 14), a chronic condition that can progress to cirrhosis or hepatocellular carcinoma rather than to acute liver failure, or they could reflect referral bias. Patients with diabetes received livers from donors who were slightly older but did not differ with regard to sex or race/ethnicity compared with donors of patients without diabetes.

Table 14 shows the percentages of patients with a given liver disease by diabetes status. For example, an alcohol-associated liver disease diagnosis was present among 21.7% of 31,074 listed patients with diabetes and 38.6% of 73,131 listed patients without diabetes. Because patients may have more than one liver disease, the percentages are not mutually exclusive and add to greater than 100%. Regarding the association of diabetes with liver disease diagnosis, it may be more informative to consider the proportion listed with diabetes according to liver disease diagnosis: 59.2% for MASLD, 37.7% for hepatocellular carcinoma, 31.6% for other causes of cirrhosis, 27.5% for HBV, 27.4% for HCV, 19.3% for alcohol-associated liver disease, and 17.5% for autoimmune liver disease. The high percentage for MASLD is not surprising, given the strong association of MASLD with diabetes (see the section Metabolic Dysfunction-Associated Steatotic Liver Disease (MASLD)). Because diabetes is a risk factor for hepatocellular carcinoma, the high percentage of cancer cases with diabetes is not surprising. A high proportion of those patients with “other causes of cirrhosis” probably also had MASLD, because the diagnosis has only more recently received attention and because the amount of fat declines with advanced cirrhosis and may be difficult to detect. It is noteworthy that the recognition of diabetes among patients with HCV was similar to that for HBV, which, as noted, has not been considered to connote as high a risk of diabetes as HCV.

Between the time of listing and transplantation, transplant candidates with diabetes are more likely to die or to be withdrawn from the waiting list, usually because of deteriorating health. These events occurred among 23.8% of those with diabetes and 17.9% of those without diabetes. The odds ratio for death or withdrawal from the waiting list for people with diabetes compared to those without diabetes was 1.43 (95% CI 1.38–1.48). Due to this increased risk of death or withdrawal, the proportion of patients with diabetes at the time of transplantation has been slightly less than at listing (Figure 3).

Compared to the previous analysis of 1994–2013 SRTR data, there has been a striking shift in the most common liver conditions leading to transplantation (1). In 1994–2013, HCV was the most common cause of liver transplantation overall and among persons with and without diabetes, but in 2014–2023, it was surpassed by alcohol-associated liver disease, MASLD, and hepatocellular carcinoma overall and among persons with diabetes. During 1994–2013, MASLD exceeded only HBV among common causes of liver transplantation overall, but in 2014–2023, MASLD was second only to alcohol-associated liver disease overall and was the most common cause among persons with diabetes. These shifts likely result from HCV treatment (see the section Viral Hepatitis (B and C)) and an increase in MASLD prevalence and its recognition (see the section Metabolic Dysfunction-Associated Steatotic Liver Disease (MASLD)).

The impact of type 2 diabetes on outcomes following liver transplantation was assessed among 106,639 U.S. adult liver transplant recipients between 2006 and 2021 in a report using SRTR data (70). The prevalence of pretransplantation type 2 diabetes was 25%. Post-transplantation mortality was significantly higher among liver transplant recipients with, compared to those without, type 2 diabetes (10.6% vs. 8.9% at 1 year and 26.2% vs. 22.0% at 5 years, p<0.0001). Patients with diabetes had a higher proportion of deaths resulting from cardiovascular causes. Association of pretransplantation type 2 diabetes with higher post-transplantation mortality remained significant after adjustment for clinicodemographic confounders (HR 1.25, 95% CI 1.21–1.28, p<0.01). Having type 2 diabetes was not associated with a risk of liver graft loss after adjustment for other factors.

New analyses on liver transplantation were also conducted among 54.4 million age-eligible Medicare beneficiaries age ≥65 years in 2022. Diabetes was defined by ICD-10-CM codes E10–E11 in any position on a claim. Liver transplantation was defined by ICD-10-CM code Z94.4, ICD, Tenth Revision, Procedure Coding System (ICD-10-PCS) codes 0FY00Z0, 0FY00Z1, or 0FY00Z2, or Current Procedural Terminology (CPT) code 47135 in any position on a claim. The prevalence of a liver transplantation diagnosis was low but was higher among persons with diagnosed diabetes (0.2%, 95% CI 0.2%–0.2%) compared with people without a diabetes diagnosis (0.1%, 95% CI 0.0%–0.1%) (Table 15). With adjustment for age, sex, race/ethnicity, and region, persons with diabetes had almost fourfold higher odds of liver transplantation compared to those without diabetes (OR 3.9, 95% CI 3.3–4.5). Higher liver transplantation prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

Similarly, new analyses on liver transplantation were conducted among 39.6 million Medicaid beneficiaries age 19–64 years in 2022, with diabetes defined using the same ICD-10-CM codes and liver transplantation using the same ICD-10-CM, ICD-10-PCS, and CPT codes as for the Medicare analyses. The prevalence of a liver transplantation diagnosis was low but was higher among persons with diagnosed diabetes (0.1%, 95% CI 0.1%–0.2%) compared with people without a diabetes diagnosis (0.0%, 95% CI 0.0%–0.1%) (Table 16). With adjustment for age, sex, race/ethnicity, and region, persons with diabetes had threefold higher odds of liver transplantation compared to those without diabetes (OR 3.1, 95% CI 2.8–3.3). Higher liver transplantation prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

## Gallbladder Disease

Gallstone disease is one of the most common digestive disorders, affecting more than 20 million adults in the United States (71). The prevalence of ultrasound-diagnosed gallstone disease was 7.9% among men and 16.6% among women based on data from the NHANES III (1988–1994), the only U.S. national abdominal ultrasonography data available (71). The prevalence of cholesterol gallstone disease is increasing, largely due to the global epidemic of obesity and diabetes-associated insulin resistance. In the U.S. population, the prevalence of symptomatic gallstone disease has doubled over the past three decades, possibly due to worsening of metabolic risk factors and the growth of laparoscopic cholecystectomy (72). Gallstone disease has a high economic burden on the U.S. health care system compared to other digestive diseases (9). Recently, in the U.S. population, gallstone disease contributed to approximately 2.2 million ambulatory care visits, 1.2 million emergency department visits, 625,000 hospital discharges, and 2,000 deaths annually, and 934,000 cholecystectomies were performed (73).

Gallstones (cholelithiasis) are concretions, usually composed of cholesterol or bilirubin, that develop in the gallbladder. The majority of gallstones in the United States and western countries are cholesterol gallstones. Gallstones may form if bile contains excess cholesterol or bilirubin or insufficient bile salts. Genetic factors and LITH (lithogenic) genes are involved in cholesterol gallstone pathogenesis, and the gastrointestinal microbiome also plays a role (74,75). Abdominal ultrasonography is the criterion standard for diagnosis of gallstones because of its accuracy and safety. The majority of gallstones remain asymptomatic. However, gallstones can block bile ducts, causing acute right upper quadrant abdominal pain, and if untreated, can lead to complications, including cholecystitis, cholangitis, and biliary pancreatitis. For symptomatic gallstones, the primary treatment is cholecystectomy, the majority of which are performed laparoscopically. Although mortality directly from gallstone disease is rare today, over the long-term, gallstone disease is associated with decreased survival. In the U.S. population over a 20-year period, persons with gallstone disease had a 30% higher mortality overall and increased mortality from cardiovascular disease and cancer (76).

Established risk factors for gallstone disease are older age, female sex, overweight and obesity, higher parity among women, and family history. Other factors that have been associated with a higher prevalence of gallstone disease are American Indian and, among women, Mexican American ethnicities, rapid weight loss, central adiposity, and cigarette smoking, while a lower prevalence of gallstones has been found in association with non-Hispanic Black and some Asian race ethnicities, higher alcohol consumption, and greater physical activity.

### Gallstone Disease and Diabetes

Diabetes is considered to be a risk factor for gallstone disease, though the relationship is complicated by their shared risk factors, such as older age and obesity. For epidemiologic studies, gallstone disease can be defined as the presence of gallstones on ultrasound or a history of a cholecystectomy. Following the introduction of gallbladder ultrasonography in the 1980s to 1990s, general population screening studies were conducted in numerous populations to estimate gallstone prevalence and identify associated factors, including in the NHANES III in the United States. Since Diabetes in America, 3rd edition, a more limited number of reports have been published on the relationship of gallstone disease with diabetes. We are not aware of new U.S. population-based studies of ultrasound-detected gallstone disease and diabetes published since Diabetes in America, 3rd edition. Table 17 summarizes four early U.S. population-based studies of the relationship of ultrasound-detected gallstone disease with diabetes. Population-based studies do not suffer from the ascertainment bias that can occur with selected patient samples. Ultrasound detects both diagnosed and undiagnosed gallstones. Diabetes was variably defined based on a self-reported health care provider diagnosis, fasting plasma glucose, or an oral glucose tolerance test (OGTT).

In the general U.S. population, both men and women reporting a diagnosis of diabetes were >50% more likely to have gallstone disease compared to persons without a diabetes diagnosis after adjustment for multiple shared risk factors (71). Men and women with undiagnosed diabetes (fasting plasma glucose ≥126 mg/dL) were approximately twice as likely to have gallstone disease as persons with normal fasting glucose (<110 mg/dL [<6.11 mmol/L]) (77). This relationship reached statistical significance only among women. Impaired fasting glucose (110–125 mg/dL) was unrelated to gallstone disease among either women or men. Two other studies were conducted in the United States. Among Mexican Americans in a Texas county, women with previously diagnosed diabetes who were receiving treatment, or with newly identified diabetes based on two fasting plasma glucose levels ≥120 mg/dL (≥6.66 mmol/L), were twice as likely to have gallstone disease (78), while there was no relationship among men. Among a diverse group of American Indians, women with diabetes (based on an OGTT) had a >40% higher prevalence of gallstone disease (79). Among men, the odds ratio was nearly as high but did not reach statistical significance (OR 1.29, 95% CI 0.96–1.72).

Among early non-U.S. population-based studies of ultrasound-detected gallstone disease, a higher prevalence of gallstone disease among persons with diabetes was found in studies from Italy, Japan, and Taiwan (80,81,82,83,84,85,86). More recent non-U.S. population-based studies of the relationship of ultrasound-detected gallstone disease with diabetes conducted in the past 15 years are included in Table 17. A Danish study found an association of fasting glucose (per 1 mmol/L) with gallstone disease (OR 1.14, 95% CI 1.05–1.24) (87). In a Chinese study, persons with a history of diabetes were >75% more likely to have gallstone disease (88). In a nationwide Chinese study of more than 10 million adults, participants with elevated fasting glucose were >40% more likely to have gallstone disease (89). A study from Chile found an association of diabetes with an increased prevalence of gallstone disease in women (OR 1.17, 95% CI 1.08–1.27) (90). In men, the odds ratio was only slightly lower but did not reach statistical significance (OR 1.14, 95% CI 0.96–1.35).

Prospective studies of incident gallstone disease can evaluate the temporal relationship with potential disease risk factors and, therefore, provide evidence for a causal association; however, few prospective studies of ultrasound-diagnosed gallstone disease have been conducted (Table 17). Two early Italian studies found positive relationships with diagnosed diabetes. In the first, during up to 7 years of follow-up, diabetes was related to incident gallstone disease with an odds ratio of 2.62 (95% CI 1.21–5.66) (91). In the second study, during a mean follow-up time of 8 years, a relationship was found among men, but not women. Among men, the odds ratio was 1.75 (95% CI 1.04–2.96) for gallstones and was even higher for cholecystectomy (OR 2.72, 95% CI 0.89–8.33), although the latter did not reach statistical significance (92). More recently, a Taiwanese study with 5 years of follow-up reported an almost 70% higher risk of gallstone disease among persons with diabetes based on elevated fasting glucose (93). Impaired fasting glucose was not statistically significantly associated with gallstone disease.

New analyses of the cross-sectional, population-based NHANES 2017–March 2020 and August 2021–August 2023 data on self-reported gallstone disease and diabetes were conducted for Diabetes in America. Participants were considered to have gallstone disease if they reported having been told by a doctor or other health professional that they had gallstones or reported having had gallbladder surgery. The age-standardized prevalence of gallstone disease increased with greater impairment of glucose metabolism and was statistically significantly higher among participants with diagnosed diabetes (25.2%, 95% CI 22.4%–28.1%) compared with participants with normal glycemia (14.8%, 95% CI 11.8%–18.4%) (Figure 4, Table 18). A higher gallstone disease prevalence among persons with diabetes was seen for most age, sex, and race/ethnicity groups, but not among Mexican American or other Hispanic adults. With adjustment for age, sex, and race/ethnicity, the odds ratio for gallstone disease remained elevated for adults with diagnosed diabetes (OR 2.6, 95% CI 2.0–3.3) and became higher for adults with undiagnosed diabetes (OR 1.7, 95% CI 1.2–2.4) relative to those with normal glycemia. A diabetes diagnosis remained associated with diagnosed gallstone disease or gallbladder surgery in a published multivariable analysis that adjusted for additional factors, including BMI (OR 1.6, 95% CI 1.2–2.1) (72). Similarly, an association of diabetes with gallstone disease was found in an earlier analysis of gallbladder ultrasonography data from adults age 20–74 years in the NHANES III (1988–1994) (1). Compared with people with normal glycemia, those with diagnosed diabetes had almost twice the prevalence of ultrasound-detected gallstone disease (Figure 4). Persons with undiagnosed diabetes and prediabetes also had higher prevalences of ultrasound-detected gallstone disease. As expected, the prevalence of a self-reported gallstone disease diagnosis or history of gallbladder surgery in the NHANES III was lower than that of ultrasound-diagnosed gallstone disease regardless of diabetes status (Figure 4). Between 1988–1994 and 2017–March 2020 / August 2021–August 2023, the prevalence of self-reported gallstone disease increased among persons with prediabetes or normal glycemia (Figure 4). Ultrasound-diagnosed gallstone disease was not measured in the NHANES 2017–March 2020 / August 2021–August 2023.

New analyses of gallstone disease were also conducted among 54.4 million age-eligible Medicare beneficiaries age ≥65 years in 2022. Diabetes was defined by ICD-10-CM codes E10–E11 in any position on a claim. Diagnosed gallstone disease was defined by an ICD-10-CM code K80 in any position on a claim. The prevalence of a gallstone disease diagnosis was higher among persons with diagnosed diabetes (3.8%, 95% CI 3.8%–3.9%) compared with people without a diabetes diagnosis (1.6%, 95% CI 1.5%–1.6%) (Table 19). With adjustment for age, sex, race/ethnicity, and region, persons with diabetes had two and a half times higher odds of gallstone disease compared with persons without diabetes (OR 2.5, 95% CI 2.4–2.6). Higher gallstone disease prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

Similarly, new analyses of gallstone disease were conducted among 39.6 million Medicaid beneficiaries age 19–64 years in 2022, with diabetes and gallstone disease defined using the same ICD-10-CM codes as for the Medicare analyses. The prevalence of a gallstone disease diagnosis was higher among people with diagnosed diabetes (2.4%, 95% CI 2.4%–2.4%) compared with people without a diabetes diagnosis (1.0%, 95% CI 1.0%–1.0%) (Table 20). With adjustment for age, sex, race/ethnicity, and region, persons with diabetes had almost two and a half times higher odds of gallstone disease compared to persons without diabetes (OR 2.4, 95% CI 2.3–2.4). Higher gallstone disease prevalences and odds ratios among persons with diabetes compared to those without diabetes were seen among all age, sex, race/ethnicity, and region groups.

### Gallstone Disease and Insulin Resistance

Cholesterol gallstones have a well-documented relationship with metabolic abnormalities, including insulin resistance, visceral adiposity, overweight and obesity, type 2 diabetes, the metabolic syndrome, and coronary heart disease (94). Gallstone disease has been proposed as the gallbladder manifestation of the metabolic syndrome (95,96). The insulin resistance and hyperinsulinemia that characterize the development of type 2 diabetes play a primary role in the metabolic syndrome.

We are not aware of new U.S. population-based studies of ultrasound-detected gallstone disease and insulin resistance that have been published since Diabetes in America, 3rd edition. Table 21 summarizes one early U.S. population-based study of the relationship of ultrasound-detected gallstone disease with insulin resistance. In studies of the general population, insulin resistance has been defined either as fasting serum insulin concentration, which is typically elevated in individuals without diabetes as a result of insulin resistance, or using the Homeostasis Model Assessment of Insulin Resistance (HOMA-IR), which is calculated from fasting insulin and fasting glucose and has been validated against the criterion standard for measurement of insulin resistance, the euglycemic hyperinsulinemic clamp (97,98). In the general U.S. population, among persons without a previous diabetes diagnosis, the prevalence of gallstone disease rose with increasing fasting serum insulin concentration among women, but not among men (77). The association in women was independent of multiple potential confounding factors, including fasting glucose, BMI, waist-to-hip ratio, and physical activity. However, the relationship of gallstone disease with insulin did not explain the increased risk of gallstones in persons with undiagnosed diabetes. This finding may have partly resulted from limitations of a cross-sectional study, in which insulin levels at the time of examination may differ from those at the time of gallstone formation, and limitations of using serum insulin concentration in people with abnormal glucose tolerance as a surrogate for insulin resistance.

Among early non-U.S. population-based studies of ultrasound-detected gallstone disease, an association of insulin resistance with gallstone disease was found in a Chilean population and among Korean men without diabetes (99,100). More recent non-U.S. population-based studies of the relationship of ultrasound-detected gallstone disease with insulin resistance conducted in the past 15 years are included in Table 21. In a study of Korean women without diabetes, gallstones on ultrasound were associated with insulin resistance among postmenopausal (OR 1.37, 95% CI 1.02–1.84), but not premenopausal, women (101). When stratified by waist circumference, the association of insulin resistance with gallstones among postmenopausal women was limited to the group with central obesity (OR 1.54, 95% CI 1.01–2.36). A Danish study found an association of gallstone disease with insulin resistance defined as either fasting insulin (per 1 mU/L; OR 1.03, 95% CI 1.01–1.05) or HOMA-IR (OR 1.18, 95% CI 1.02–1.36) (87). In this study, biomarkers of insulin resistance explained an association of BMI with gallstone disease prevalence. Persons with the metabolic syndrome had a >50% higher prevalence of gallstone disease.

In the one early prospective study of gallstone disease and insulin resistance of which the authors are aware, an increased risk of gallstone disease was found with insulin resistance among persons without diabetes (Table 21). In this Italian nested case-control study, an insulin level in the highest quintile was associated with incident gallstone disease with an odds ratio of 2.64 (102).

In conclusion, among published population-based studies utilizing gallbladder ultrasonography, a fairly consistent association of gallstone disease with diabetes independent of adiposity and other factors has been observed. The increased risk has been as high as double among people with diabetes. The relationship has been more consistent among women than men. This may result from decreased statistical power to detect such a relationship in men, who have a lower prevalence of gallstones. In addition, although the majority of gallstones in the United States are cholesterol stones (103), the proportion of cholesterol stones is lower in men than in women (104,105). An exception with regard to sex difference was a stronger relationship among men in one of the Italian studies of incident gallstone disease (92). In the new age-standardized analyses of the U.S. population for Diabetes in America discussed above, a similar pattern of increasing diagnosed gallstone disease prevalence with greater impairment of glucose metabolism was observed overall and among sex, age, and race/ethnicity groups. In addition, the prevalence of diagnosed gallstone disease was higher among Medicare and Medicaid beneficiaries with diagnosed diabetes compared to persons without a diabetes diagnosis overall and among demographic groups. An association of insulin resistance with gallstone disease has been shown among persons without overt diabetes (100,101,102). Insulin resistance may be the link between diabetes and gallstone disease.

### Acute Cholecystitis and Diabetes

Gallstone disease can be complicated by acute cholecystitis, a potentially life-threatening condition, most often due to cystic duct obstruction by gallstones. Persons with diabetes have an increased risk of biliary disease, including acute cholecystectomy (106). However, it is generally considered that patients with diabetes who are asymptomatic for gallstone disease do not benefit from screening for gallstones and that cholecystectomy should only be performed in cases of symptomatic cholelithiasis, as in the general population (107).

## Conclusion

This article reviews and presents new data from national cohorts on the overlap of diabetes with common chronic liver and gallbladder diseases, including MASLD, viral hepatitis, cirrhosis, and gallstone disease. MASLD recently replaced the term NAFLD to identify SLD in the presence of at least one cardiometabolic risk factor associated with insulin resistance (e.g., obesity, diabetes, atherogenic dyslipidemia, or hypertension) without other identifiable causes of steatosis. In the U.S. adult population, the prevalence of transient elastography-assessed MASLD was greater among persons with diagnosed and undiagnosed diabetes and prediabetes compared to persons with normal glycemia. The age-standardized prevalence of elevated liver stiffness was higher among participants with diagnosed diabetes and undiagnosed diabetes compared with participants with normal glycemia. The American Diabetes Association recommends stepwise screening of adults with type 2 diabetes or prediabetes, especially those with obesity or cardiometabolic risk factors or established cardiovascular disease, for clinically significant liver fibrosis using the fibrosis-4 index (FIB-4) and transient elastography or the enhanced liver fibrosis (ELF) blood biomarker with referral to a gastroenterologist/hepatologist as appropriate (36). Diabetes and insulin resistance are closely linked to the development and progression of MASLD, which comprises the liver manifestation of a broader multisystem condition with an underlying etiology of insulin resistance that also includes obesity, diabetes, hyperlipidemia, and hypertension.

HCV infection is now curable in many cases when treated with direct-acting antiviral agents, so it is becoming a less common cause of end-stage liver disease, except among persons who remain undiagnosed or untreated. Diabetes is found in a high proportion of patients with cirrhosis regardless of the liver disease etiology. Among patients listed as candidates for liver transplantation, 30% carry a diagnosis of diabetes, which is double the proportion of 30 years ago. Patients with diabetes awaiting liver transplantation have a 40% higher risk of removal from the waiting list due to dying before transplantation or to deteriorating health resulting in medical contraindications to transplantation.

In the U.S. population, the prevalence of symptomatic gallstone disease increased with greater impairment of glucose metabolism and was higher among persons with diagnosed diabetes compared to persons with normal glycemia. Published epidemiologic studies of ultrasound-detected gallstone disease likewise indicate a fairly consistent association of gallstone disease with diabetes independent of adiposity or other shared risk factors. An association of insulin resistance with gallstone disease has also been shown among persons without diabetes and may be a link between diabetes and gallstone disease.

The new data presented in this article reflect the changing epidemiology of liver disease in relation to diabetes as obesity-related liver disease has become a growing contributor to liver disease in the United States and is increasingly recognized as a systemic condition. The much lower prevalence of documented MASLD diagnoses from claims data compared with the screen prevalence from survey data indicates that most people with MASLD are undiagnosed and untreated. The extent of undiagnosed MASLD emphasizes the need for noninvasive screening among persons with diabetes and prediabetes who may benefit from lifestyle modifications and emerging drug treatment strategies.

## List of Abbreviations

A1C: glycated hemoglobin
BMI: body mass index
CAP: controlled attenuation parameter
CI: confidence interval
CMS: Centers for Medicare and Medicaid Services
CPT: Current Procedural Terminology
HBcAb: hepatitis B core antibody
HBsAg: hepatitis B surface antigen
HBV: hepatitis B virus
HCV: hepatitis C virus
HDL: high-density lipoprotein
HOMA-IR: Homeostasis Model Assessment of Insulin Resistance
HR: hazard ratio
ICD: International Classification of Diseases
ICD-10-CM: ICD, Tenth Revision, Clinical Modification
ICD-10-PCS: ICD, Tenth Revision, Procedure Coding System
MASH: metabolic dysfunction-associated steatohepatitis
MASLD: metabolic dysfunction-associated steatotic liver disease
MELD: Model for End-Stage Liver Disease
MetALD: metabolic dysfunction and alcohol-associated steatotic liver disease
NAFLD: nonalcoholic fatty liver disease
NHANES: National Health and Nutrition Examination Survey
OGTT: oral glucose tolerance test
OR: odds ratio
RNA: ribonucleic acid
SLD: steatotic liver disease
SRTR: Scientific Registry of Transplant Recipients

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Glucose: mg/dL x 0.0555 = mmol/L

Insulin: µIU/mL x 6 = pmol/L

## Acknowledgments

This is an update of: Ruhl CE, Clark JM, Everhart JE. Liver and Gallbladder Disease in Diabetes. Chapter 26 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 26.1–26.23.

The authors thank Danita Byrd-Clark for assistance with the programming of Scientific Registry of Transplant Recipient data, Ying Li and Danita Byrd-Clark for assistance with programming of National Health and Nutrition Examination Survey data, and Helen Corns for assistance with programming of CMS Medicare 5% sample and CMS Medicaid data.

## Article History

Received in final form on March 17, 2026.

## Disclaimer

The findings and conclusions in this report are those of the authors and do not necessarily represent the official position of the National Institutes of Health.

## References

1 Ruhl CE, Clark JM, Everhart JE. Liver and gallbladder disease in diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. 2018; 26.1-26.23. https://www.ncbi.nlm.nih.gov/books/NBK568000/
2 National Center for Health Statistics. National Health and Nutrition Examination Survey (NHANES). Accessed March 2026. https://www.cdc.gov/nchs/nhanes/?CDC_AAref_Val=https://www.cdc.gov/nchs/nhanes/index.htm
3 National Center for Health Statistics. National Health and Nutrition Examination Survey 2021 Liver Ultrasound Transient Elastography Procedures Manual. 2021. Accessed March 2026. https://wwwn.cdc.gov/nchs/data/nhanes/public/2021/manuals/2021-LUTE-Procedures-508.pdf
4 Centers for Medicare & Medicaid Services. Chronic Conditions Data Warehouse. Accessed March 2026. https://www2.ccwdata.org/web/guest/home/
5 Research Data Assistance Center (ResDAC). Getting Started with CMS Data. Accessed March 2026. https://resdac.org/getting-started-cms-data#who-is-in-the-data
6 Scientific Registry of Transplant Recipients. About SRTR Standard Analysis Files (SAFs). Accessed March 2026. https://www.srtr.org/requesting-data/about-srtr-standard-analysis-files-safs/
7 Rinella ME, Lazarus JV, Ratziu V, et al. A multisociety Delphi consensus statement on new fatty liver disease nomenclature. Hepatology. 2023;78(6):1966-1986. doi:10.1097/HEP.0000000000000520 37363821
8 Kanwal F, Neuschwander-Tetri BA, Loomba R, Rinella ME. Metabolic dysfunction-associated steatotic liver disease: update and impact of new nomenclature on the American Association for the Study of Liver Diseases Practice Guidance on Nonalcoholic Fatty Liver Disease. Hepatology. 2024;79(5):1212-1219. doi:10.1097/HEP.0000000000000670 38445559
9 Peery AF, Murphy CC, Anderson C, et al. Burden and cost of gastrointestinal, liver, and pancreatic diseases in the United States: update 2024. Gastroenterology. 2025;168(5):1000-1024. doi:10.1053/j.gastro.2024.12.029 39920892
10 Unalp-Arida A, Ruhl CE. Burden of nonmalignant liver and pancreatic diseases in the United States population: rates and trends. Clin Gastroenterol Hepatol. 2025;23(10):1679-1692.e9. doi:10.1016/j.cgh.2025.01.026 40147498
11 Murphy SL, Kochanek KD, Xu J, Arias E. Mortality in the United States, 2023. NCHS Data Brief. 2024;(521):CS356116. doi:10.15620/cdc/170564 39819663
12 Murphy SL, Kochanek KD, Xu J, Arias E. Deaths: final data for 2021. Natl Vital Stat Rep. 2024;73(8):1-139. doi:10.15620/cdc/158787 40305404
13 Unalp-Arida A, Ruhl CE. Noninvasive fatty liver markers predict liver disease mortality in the U.S. population. Hepatology. 2016;63(4):1170-1183. doi:10.1002/hep.28390 26663021
14 Unalp-Arida A, Ruhl CE. Patatin-like phospholipase domain-containing protein 3 I148M and liver fat and fibrosis scores predict liver disease mortality in the U.S. population. Hepatology. 2020;71(3):820-834. doi:10.1002/hep.31032 31705824
15 Sanyal AJ, Van Natta ML, Clark J, et al. Prospective study of outcomes in adults with nonalcoholic fatty liver disease. N Engl J Med. 2021;385(17):1559-1569. doi:10.1056/NEJMoa2029349 34670043
16 Gawrieh S, Vilar-Gomez E, Wilson LA, et al. Increases and decreases in liver stiffness measurement are independently associated with the risk of liver-related events in NAFLD. J Hepatol. 2024;81(4):600-608. doi:10.1016/j.jhep.2024.05.008 38762169
17 Rinella ME, Neuschwander-Tetri BA, Siddiqui MS, et al. AASLD Practice Guidance on the Clinical Assessment and Management of Nonalcoholic Fatty Liver Disease. Hepatology. 2023;77(5):1797-1835. doi:10.1097/HEP.0000000000000323 36727674
18 Younossi ZM, Paik JM, Stepanova M, Ong J, Alqahtani S, Henry L. Clinical profiles and mortality rates are similar for metabolic dysfunction-associated steatotic liver disease and non-alcoholic fatty liver disease. J Hepatol. 2024;80(5):694-701. doi:10.1016/j.jhep.2024.01.014 38286339
19 Sasso M, Miette V, Sandrin L, Beaugrand M. The controlled attenuation parameter (CAP): a novel tool for the non-invasive evaluation of steatosis using Fibroscan. Clin Res Hepatol Gastroenterol. 2012;36(1):13-20. doi:10.1016/j.clinre.2011.08.001 21920839
20 Fabrellas N, Hernández R, Graupera I, et al. Prevalence of hepatic steatosis as assessed by controlled attenuation parameter (CAP) in subjects with metabolic risk factors in primary care. A population-based study. PLoS One. 2018;13(9):e0200656. doi:10.1371/journal.pone.0200656 30226889
21 Unalp-Arida A, Ruhl CE. Prevalence of metabolic dysfunction-associated steatotic liver disease and fibrosis defined by liver elastography in the United States using National Health and Nutrition Examination Survey 2017–March 2020 and August 2021–August 2023 data. Hepatology. 2025;82(5):1256-1273. doi:10.1097/HEP.0000000000001211 39724144
22 Siddiqui MS, Vuppalanchi R, Van Natta ML, et al. Vibration-controlled transient elastography to assess fibrosis and steatosis in patients with nonalcoholic fatty liver disease. Clin Gastroenterol Hepatol. 2019;17(1):156-163.e2. doi:10.1016/j.cgh.2018.04.043 29705261
23 Eddowes PJ, Sasso M, Allison M, et al. Accuracy of FibroScan controlled attenuation parameter and liver stiffness measurement in assessing steatosis and fibrosis in patients with nonalcoholic fatty liver disease. Gastroenterology. 2019;156(6):1717-1730. doi:10.1053/j.gastro.2019.01.042 30689971
24 Lee BP, Dodge JL, Terrault NA. National prevalence estimates for steatotic liver disease and subclassifications using consensus nomenclature. Hepatology. 2024;79(3):666-673. doi:10.1097/HEP.0000000000000604 37732946
25 Unalp-Arida A, Ruhl CE. Prepandemic prevalence estimates of fatty liver disease and fibrosis defined by liver elastography in the United States. Dig Dis Sci. 2023;68(4):1237-1252. doi:10.1007/s10620-022-07707-1 36173583
26 Lee EJ, Choi M, Ahn SB, et al. Prevalence of nonalcoholic fatty liver disease in pediatrics and adolescents: a systematic review and meta-analysis. World J Pediatr. 2024;20(6):569-580. doi:10.1007/s12519-024-00814-1 38771552
27 Braffett BH, Crume T, Bjornstad P, Dabelea D. Diabetes in children and adolescents. In: Lawrence JM, Casagrande SS, Herman WH, Wexler D, J., Cefalu WT, eds. Diabetes in America. eBook. National Institute of Diabetes and Digestive and Kidney Diseases; 2025. https://www.ncbi.nlm.nih.gov/books/NBK619869/
28 Xanthakos SA, Ibrahim SH, Adams K, et al. AASLD Practice Statement on the Evaluation and Management of Metabolic Dysfunction-Associated Steatotic Liver Disease in Children. Hepatology. 2025;82(5):1352-1394. doi:10.1097/HEP.0000000000001368 40300071
29 Golabi P, Paik JM, Kumar A, et al. Nonalcoholic fatty liver disease (NAFLD) and associated mortality in individuals with type 2 diabetes, pre-diabetes, metabolically unhealthy, and metabolically healthy individuals in the United States. Metabolism. 2023;146:155642. doi:10.1016/j.metabol.2023.155642 37380016
30 Kanwal F, Kramer JR, Li L, et al. Effect of metabolic traits on the risk of cirrhosis and hepatocellular cancer in nonalcoholic fatty liver disease. Hepatology. 2020;71(3):808-819. doi:10.1002/hep.31014 31675427
31 Younossi ZM, Corey KE, Lim JK. AGA Clinical Practice Update on Lifestyle Modification Using Diet and Exercise to Achieve Weight Loss in the Management of Nonalcoholic Fatty Liver Disease: Expert Review. Gastroenterology. 2021;160(3):912-918. doi:10.1053/j.gastro.2020.11.051 33307021
32 Kim D, Konyn P, Cholankeril G, Ahmed A. Physical activity is associated with nonalcoholic fatty liver disease and significant fibrosis measured by FibroScan. Clin Gastroenterol Hepatol. 2022;20(6):e1438-e1455. doi:10.1016/j.cgh.2021.06.029 34214678
33 Vilar-Gomez E, Nephew LD, Vuppalanchi R, et al. High-quality diet, physical activity, and college education are associated with low risk of NAFLD among the US population. Hepatology. 2022;75(6):1491-1506. doi:10.1002/hep.32207 34668597
34 Heredia NI, Zhang X, Balakrishnan M, et al. Physical activity and diet quality in relation to non-alcoholic fatty liver disease: a cross-sectional study in a representative sample of U.S. adults using NHANES 2017–2018. Prev Med. 2022;154:106903. doi:10.1016/j.ypmed.2021.106903 34861339
35 U.S. Department of Health and Human Services. Physical Activity Guidelines for Americans. 2018. Accessed March, 2026. https://odphp.health.gov/sites/default/files/2019-09/Physical_Activity_Guidelines_2nd_edition.pdf
36 American Diabetes Association Professional Practice Committee for Diabetes. 4. Comprehensive Medical Evaluation and Assessment of Comorbidities: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S61-S88. doi:10.2337/dc26-S004 41358897
37 American Diabetes Association Professional Practice Committee for Diabetes. 5. Facilitating Positive Health Behaviors and Well-being to Improve Health Outcomes: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S89-S131. doi:10.2337/dc26-S005 41358898
38 Kim D, Danpanichkul P, Wijarnpreecha K, Loomba R, Ahmed A. Social determinants of health in metabolic dysfunction-associated steatotic liver disease and all-cause/cause-specific mortality. Aliment Pharmacol Ther. 2026;63(5):662-671. doi:10.1111/apt.70409 41090478
39 White DL, Ratziu V, El-Serag HB. Hepatitis C infection and risk of diabetes: a systematic review and meta-analysis. J Hepatol. 2008;49(5):831-844. doi:10.1016/j.jhep.2008.08.006 18814931
40 Mehta SH, Brancati FL, Sulkowski MS, Strathdee SA, Szklo M, Thomas DL. Prevalence of type 2 diabetes mellitus among persons with hepatitis C virus infection in the United States. Ann Intern Med. 2000;133(8):592-599. doi:10.7326/0003-4819-133-8-200010170-00009 11033586
41 Mehta SH, Brancati FL, Strathdee SA, et al. Hepatitis C virus infection and incident type 2 diabetes. Hepatology. 2003;38(1):50-56. doi:10.1053/jhep.2003.50291 12829986
42 Wang C-S, Wang S-T, Yao W-J, Chang T-T, Chou P. Hepatitis C virus infection and the development of type 2 diabetes in a community-based longitudinal study. Am J Epidemiol. 2007;166(2):196-203. doi:10.1093/aje/kwm061 17496314
43 Montenegro L, De Michina A, Misciagna G, Guerra V, Di Leo A. Virus C hepatitis and type 2 diabetes: a cohort study in southern Italy. Am J Gastroenterol. 2013;108(7):1108-1111. doi:10.1038/ajg.2013.90 23567360
44 Chen Y, Ji H, Shao J, et al. Different hepatitis C virus infection statuses show a significant risk of developing type 2 diabetes mellitus: a network meta-analysis. Dig Dis Sci. 2020;65(7):1940-1950. doi:10.1007/s10620-019-05918-7 31758432
45 Younossi ZM, Henry L, Ong PJ, et al. Systematic review with meta-analysis: extrahepatic manifestations in chronic hepatitis C virus-infected patients in East Asia. Aliment Pharmacol Ther. 2019;49(6):644-653. doi:10.1111/apt.15131 30761562
46 Younossi Z, Park H, Henry L, Adeyemi A, Stepanova M. Extrahepatic manifestations of hepatitis C: a meta-analysis of prevalence, quality of life, and economic burden. Gastroenterology. 2016;150(7):1599-1608. doi:10.1053/j.gastro.2016.02.039 26924097
47 Fabiani S, Fallahi P, Ferrari SM, Miccoli M, Antonelli A. Hepatitis C virus infection and development of type 2 diabetes mellitus: systematic review and meta-analysis of the literature. Rev Endocr Metab Disord. 2018;19(4):405-420. doi:10.1007/s11154-017-9440-1 29322398
48 Mukhtar NA, Ness EM, Jhaveri M, et al. Epidemiologic features of a large hepatitis C cohort evaluated in a major health system in the western United States. Ann Hepatol. 2019;18(2):360-365. doi:10.1016/j.aohep.2018.12.003 31053542
49 Büsch K, Waldenström J, Lagging M, et al. Prevalence and comorbidities of chronic hepatitis C: a nationwide population-based register study in Sweden. Scand J Gastroenterol. 2017;52(1):61-68. doi:10.1080/00365521.2016.1228119 27598393
50 Jeong D, Karim ME, Wong S, et al. Impact of HCV infection and ethnicity on incident type 2 diabetes: findings from a large population-based cohort in British Columbia. BMJ Open Diabetes Res Care. 2021;9(1):e002145. doi:10.1136/bmjdrc-2021-002145 34099439
51 Choi HY, Kim Y, Cho H, Kim BH, Ki M. Risk of diabetes in viral hepatitis B or C patients compared to that in noninfected individuals in Korea, 2002–2013: a population-based cohort study. J Viral Hepat. 2018;25(3):272-280. doi:10.1111/jvh.12815 29080254
52 Watt GP, Vatcheva KP, Beretta L, et al. Hepatitis C virus in Mexican Americans: a population-based study reveals relatively high prevalence and negative association with diabetes. Epidemiol Infect. 2016;144(2):297-305. doi:10.1017/S0950268815001247 26088260
53 Schnier C, Wild S, Kurdi Z, Povey C, Goldberg DJ, Hutchinson SJ. Matched population-based study examining the risk of type 2 diabetes in people with and without diagnosed hepatitis C virus infection. J Viral Hepat. 2016;23(8):596-605. doi:10.1111/jvh.12520 26910297
54 Cacoub P, Desbois AC, Comarmond C, Saadoun D. Impact of sustained virological response on the extrahepatic manifestations of chronic hepatitis C: a meta-analysis. Gut. 2018;67(11):2025-2034. doi:10.1136/gutjnl-2018-316234 29703790
55 Chen B, Iqbal U, Desai SK, et al. The role of treatment of hepatitis C with direct-acting antiviral agents on glycaemic control in diabetic patients: an updated systematic review and meta-analysis. J Viral Hepat. 2024;31(10):633-642. doi:10.1111/jvh.13984 39046172
56 Maeno T, Okumura A, Ishikawa T, et al. Mechanisms of increased insulin resistance in non-cirrhotic patients with chronic hepatitis C virus infection. J Gastroenterol Hepatol. 2003;18(12):1358-1363. doi:10.1046/j.1440-1746.2003.03179.x 14675263
57 Jeong D, Wong S, Karim ME, et al. Direct-acting antivirals and risk of hepatitis C extrahepatic manifestations. JAMA Netw Open. 2025;8(6):e2514631. doi:10.1001/jamanetworkopen.2025.14631 40498486
58 Ruhl CE, Menke A, Cowie CC, Everhart JE. Relationship of hepatitis C virus infection with diabetes in the U.S. population. Hepatology. 2014;60(4):1139-1149. doi:10.1002/hep.27047 24500979
59 Razi B, Alizadeh S, Omidkhoda A, Imani D, Rezaei R. Association of chronic hepatitis B infection with metabolic syndrome and its components: meta-analysis of observational studies. Diabetes Metab Syndr. 2017;11(Suppl 2):S939-S947. doi:10.1016/j.dsx.2017.07.020 28701286
60 Bloodworth JM, Jr. Diabetes mellitus and cirrhosis of the liver. Arch Intern Med. 1961;108:695-701. doi:10.1001/archinte.1961.03620110035006 13870119
61 Castera L, Cusi K. Diabetes and cirrhosis: current concepts on diagnosis and management. Hepatology. 2023;77(6):2128-2146. doi:10.1097/HEP.0000000000000263 36631005
62 Younossi ZM, Golabi P, de Avila L, et al. The global epidemiology of NAFLD and NASH in patients with type 2 diabetes: a systematic review and meta-analysis. J Hepatol. 2019;71(4):793-801. doi:10.1016/j.jhep.2019.06.021 31279902
63 Ciardullo S, Monti T, Perseghin G. High prevalence of advanced liver fibrosis assessed by transient elastography among U.S. adults with type 2 diabetes. Diabetes Care. 2021;44(2):519-525. doi:10.2337/dc20-1778 33303638
64 Lee WG, Wells CI, McCall JL, Murphy R, Plank LD. Prevalence of diabetes in liver cirrhosis: a systematic review and meta-analysis. Diabetes Metab Res Rev. 2019;35(6):e3157. doi:10.1002/dmrr.3157 30901133
65 Vaz J, Eriksson B, Strömberg U, Buchebner D, Midlöv P. Incidence, aetiology and related comorbidities of cirrhosis: a Swedish population-based cohort study. BMC Gastroenterol. 2020;20(1):84. doi:10.1186/s12876-020-01239-6 32245414
66 Valery PC, McPhail S, Stuart KA, et al. Changing prevalence of aetiological factors and comorbidities among Australians hospitalised for cirrhosis. Intern Med J. 2021;51(5):691-698. doi:10.1111/imj.14809 32096890
67 Ahn SB, Powell EE, Russell A, et al. Type 2 diabetes: a risk factor for hospital readmissions and mortality in Australian patients with cirrhosis. Hepatol Commun. 2020;4(9):1279-1292. doi:10.1002/hep4.1536 32923832
68 Rodríguez-Escaja C, Navascués CÁ, González-Diéguez L, et al. Diabetes is not associated with an increased risk of hepatocellular carcinoma in patients with alcoholic or hepatitis C virus cirrhosis. Rev Esp Enferm Dig. 2021;113(7):505-511. doi:10.17235/reed.2020.6953/2020 33244982
69 Goh GB-B, Pan A, Chow W-C, Yuan J-M, Koh W-P. Association between diabetes mellitus and cirrhosis mortality: the Singapore Chinese Health Study. Liver Int. 2017;37(2):251-258. doi:10.1111/liv.13241 27566448
70 Stepanova M, Kumar A, Brandt P, et al. Impact of type 2 diabetes on the outcomes of solid organ transplantations in the U.S.: data from a national registry. Diabetes Care. 2023;46(12):2162-2170. doi:10.2337/dc23-1085 37748128
71 Everhart JE, Khare M, Hill M, Maurer KR. Prevalence and ethnic differences in gallbladder disease in the United States. Gastroenterology. 1999;117(3):632-639. doi:10.1016/s0016-5085(99)70456-7 10464139
72 Unalp-Arida A, Ruhl CE. Increasing gallstone disease prevalence and associations with gallbladder and biliary tract mortality in the US. Hepatology. 2023;77(6):1882-1895. doi:10.1097/HEP.0000000000000264 36631004
73 Unalp-Arida A, Ruhl CE. Burden of gallstone disease in the United States population: prepandemic rates and trends. World J Gastrointest Surg. 2024;16(4):1130-1148. doi:10.4240/wjgs.v16.i4.1130 38690054
74 Wang HH, Portincasa P, Afdhal NH, Wang DQH. Lith genes and genetic analysis of cholesterol gallstone formation. Gastroenterol Clin North Am. 2010;39(2):185-207, vii-viii. doi:10.1016/j.gtc.2010.02.007
75 Di Ciaula A, Wang DQ-H, Portincasa P. An update on the pathogenesis of cholesterol gallstone disease. Curr Opin Gastroenterol. 2018;34(2):71-80. doi:10.1097/MOG.0000000000000423 29283909
76 Ruhl CE, Everhart JE. Gallstone disease is associated with increased mortality in the United States. Gastroenterology. 2011;140(2):508-516. doi:10.1053/j.gastro.2010.10.060 21075109
77 Ruhl CE, Everhart JE. Association of diabetes, serum insulin, and C-peptide with gallbladder disease. Hepatology. 2000;31(2):299-303. doi:10.1002/hep.510310206 10655249
78 Hanis CL, Hewett-Emmett D, Kubrusly LF, et al. An ultrasound survey of gallbladder disease among Mexican Americans in Starr County, Texas: frequencies and risk factors. Ethn Dis. 1993;3(1):32-43.8508103
79 Everhart JE, Yeh F, Lee ET, et al. Prevalence of gallbladder disease in American Indian populations: findings from the Strong Heart Study. Hepatology. 2002;35(6):1507-1512. doi:10.1053/jhep.2002.33336 12029637
80 Attili AF, Capocaccia R, Carulli N, et al. Factors associated with gallstone disease in the MICOL experience. Multicenter Italian Study on Epidemiology of Cholelithiasis. Hepatology. 1997;26(4):809-818. doi:10.1002/hep.510260401 9328297
81 De Santis A, Attili AF, Ginanni Corradini S, et al. Gallstones and diabetes: a case-control study in a free-living population sample. Hepatology. 1997;25(4):787-790. doi:10.1002/hep.510250401 9096577
82 Kono S, Shinchi K, Ikeda N, Yanai F, Imanishi K. Prevalence of gallstone disease in relation to smoking, alcohol use, obesity, and glucose tolerance: a study of self-defense officials in Japan. Am J Epidemiol. 1992;136(7):787-794. doi:10.1093/aje/136.7.787 1442744
83 Kono S, Shinchi K, Todoroki I, et al. Gallstone disease among Japanese men in relation to obesity, glucose intolerance, exercise, alcohol use, and smoking. Scand J Gastroenterol. 1995;30(4):372-376. doi:10.3109/00365529509093293 7610355
84 Sasazuki S, Kono S, Todoroki I, et al. Impaired glucose tolerance, diabetes mellitus, and gallstone disease: an extended study of male self-defense officials in Japan. Eur J Epidemiol. 1999;15(3):245-251. doi:10.1023/a:1007506627119 10395054
85 Chen C-H, Huang M-H, Yang J-C, et al. Prevalence and risk factors of gallstone disease in an adult population of Taiwan: an epidemiological survey. J Gastroenterol Hepatol. 2006;21(11):1737-1743. doi:10.1111/j.1440-1746.2006.04381.x 16984599
86 Liu C-M, Tung T-H, Chou P, et al. Clinical correlation of gallstone disease in a Chinese population in Taiwan: experience at Cheng Hsin General Hospital. World J Gastroenterol. 2006;12(8):1281-1286. doi:10.3748/wjg.v12.i8.1281 16534886
87 Shabanzadeh DM. New determinants for gallstone disease? Dan Med J. 2018;65(2):B5438. https://ugeskriftet.dk/dmj/new-determinants-gallstone-disease 29393043
88 Lv F, Wang G, Ding D, et al. Epidemiological survey to determine the prevalence of cholecystolithiasis in Uyghur, Kazakh, and Han ethnic groups in the Xinjiang Uyghur Autonomous Region of China: cross-sectional studies. BMC Gastroenterol. 2021;21(1):125. doi:10.1186/s12876-021-01677-w 33736598
89 Song Y, Ma Y, Xie F-C, et al. Age, gender, geographic and clinical differences for gallstones in China: a nationwide study. Ann Transl Med. 2022;10(13):735. doi:10.21037/atm-21-6186 35957733
90 Rodriguez Gatta D, Huidobro L, Petermann-Rocha F, et al. Sex disparities in gallstone disease: insights from the MAUCO prospective population-based cohort study. BMJ Open Gastroenterol. 2024;11(1):e001457. doi:10.1136/bmjgast-2024-001457 39343441
91 Misciagna G, Leoci C, Guerra V, et al. Epidemiology of cholelithiasis in southern Italy. Part II: risk factors. Eur J Gastroenterol Hepatol. 1996;8(6):585-593. doi:10.1097/00042737-199606000-00017 8823575
92 Festi D, Dormi A, Capodicasa S, et al. Incidence of gallstone disease in Italy: results from a multicenter, population-based Italian study (the MICOL project). World J Gastroenterol. 2008;14(34):5282-5289. doi:10.3748/wjg.14.5282 18785280
93 Chen J-Y, Hsu C-T, Liu J-H, Tung T-H. Clinical predictors of incident gallstone disease in a Chinese population in Taipei, Taiwan. BMC Gastroenterol. 2014;14:83. doi:10.1186/1471-230X-14-83 24775330
94 Di Ciaula A, Wang DQ-H, Portincasa P. Cholesterol cholelithiasis: part of a systemic metabolic disease, prone to primary prevention. Expert Rev Gastroenterol Hepatol. 2019;13(2):157-171. doi:10.1080/17474124.2019.1549988 30791781
95 Diehl AK. Cholelithiasis and the insulin resistance syndrome. Hepatology. 2000;31(2):528-530. doi:10.1002/hep.510310238 10655281
96 Grundy SM. Cholesterol gallstones: a fellow traveler with metabolic syndrome? Am J Clin Nutr. 2004;80(1):1-2. doi:10.1093/ajcn/80.1.1 15213019
97 Matthews DR, Hosker JP, Rudenski AS, Naylor BA, Treacher DF, Turner RC. Homeostasis model assessment: insulin resistance and β-cell function from fasting plasma glucose and insulin concentrations in man. Diabetologia. 1985;28(7):412-419. doi:10.1007/BF00280883 3899825
98 Hanson RL, Pratley RE, Bogardus C, et al. Evaluation of simple indices of insulin sensitivity and insulin secretion for use in epidemiologic studies. Am J Epidemiol. 2000;151(2):190-198. doi:10.1093/oxfordjournals.aje.a010187 10645822
99 Nervi F, Miquel JF, Alvarez M, et al. Gallbladder disease is associated with insulin resistance in a high risk Hispanic population. J Hepatol. 2006;45(2):299-305. doi:10.1016/j.jhep.2006.01.026 16516330
100 Chang Y, Sung E, Ryu S, Park YW, Jang YM, Park M. Insulin resistance is associated with gallstones even in non-obese, non-diabetic Korean men. J Korean Med Sci. 2008;23(4):644-650. doi:10.3346/jkms.2008.23.4.644 18756051
101 Kim SS, Lee JG, Kim DW, et al. Insulin resistance as a risk factor for gallbladder stone formation in Korean postmenopausal women. Korean J Intern Med. 2011;26(3):285-293. doi:10.3904/kjim.2011.26.3.285 22016589
102 Misciagna G, Guerra V, Di Leo A, Correale M, Trevisan M. Insulin and gall stones: a population case control study in southern Italy. Gut. 2000;47(1):144-147. doi:10.1136/gut.47.1.144 10861277
103 Diehl AK, Schwesinger WH, Holleman DR, Jr., Chapman JB, Kurtin WE. Gallstone characteristics in Mexican Americans and non-Hispanic Whites. Dig Dis Sci. 1994;39(10):2223-2228. doi:10.1007/BF02090375 7924746
104 Trotman BW, Soloway RD. Pigment vs cholesterol cholelithiasis: clinical and epidemiological aspects. Am J Dig Dis. 1975;20(8):735-740. doi:10.1007/BF01070831 1155413
105 Diehl AK, Schwesinger WH, Holleman DR, Jr., Chapman JB, Kurtin WE. Clinical correlates of gallstone composition: distinguishing pigment from cholesterol stones. Am J Gastroenterol. 1995;90(6):967-972.7771432
106 Noel RA, Braun DK, Patterson RE, Bloomgren GL. Increased risk of acute pancreatitis and biliary disease observed in patients with type 2 diabetes: a retrospective cohort study. Diabetes Care. 2009;32(5):834-838. doi:10.2337/dc08-1755 19208917
107 Aucott JN, Cooper GS, Bloom AD, Aron DC. Management of gallstones in diabetic patients. Arch Intern Med. 1993;153(9):1053-1058. doi:10.1001/archinte.1993.00410090019003 8481073

FIGURE 1.

Age-Standardized Prevalence of Metabolic Dysfunction-Associated Steatotic Liver Disease (MASLD) and Elevated Liver Stiffness Diagnosed by Liver Elastography, by Diabetes Status, U.S., 2017–March 2020 and August 2021–August 2023.

Diagnosed diabetes is defined as self-reported health care provider diagnosis; undiagnosed diabetes is defined as A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Error bars represent 95% confidence intervals. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin.

* MASLD is defined as controlled attenuation parameter >300 dB/m and alcohol intake of <3 drinks/day for men or <2 drinks/day for women.

^†^ Elevated liver stiffness is defined as >8 kPa.

SOURCE: National Health and Nutrition Examination Surveys 2017–March 2020 and August 2021–August 2023

Bar graph showing that adults with diagnosed and undiagnosed diabetes had significantly higher prevalences of steatotic liver disease and elevated liver stiffness compared to adults with prediabetes or normal glucose.

FIGURE 2.

Age-Standardized Prevalence of Hepatitis B and Hepatitis C, by Diabetes Status, U.S., 2011–2020.

Diabetes is defined as self-reported health care provider diagnosis or A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Error bars represent 95% confidence intervals. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; RNA, ribonucleic acid.

^1^ Relative standard error >40%–50%

SOURCE: National Health and Nutrition Examination Surveys 2011–March 2020

Bar graph showing that the prevalence of hepatitis B core antibodies was higher among those with diabetes and prediabetes although not significantly different from adults with normal glucose. Prevalence of hepatitis C antibodies was similar by glucose status.

FIGURE 3.

Prevalence of Diabetes Among Adult Liver Transplant Candidates, by Listing and Transplant Years, U.S., 1994–2023.

Diabetes status is self-reported.

* Listing year is defined as the year a patient was added to the national liver transplant waiting list.

SOURCE: Standard Analysis File of the Scientific Registry of Transplant Recipients 1994–2023

Line graph showing that the prevalence of diabetes among adult liver candidates increased from about 14% in 1994 to 28% in 2023.

FIGURE 4.

Age-Standardized Prevalence of Ultrasound-Detected Gallstone Disease and Diagnosed Gallstone Disease or Gallbladder Surgery, by Diabetes Status, U.S., 1988–1994 and 2017–March 2020 and August 2021–August 2023.

Diagnosed diabetes is defined as self-reported health care provider diagnosis; undiagnosed diabetes is defined as A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Ultrasound-detected gallstone disease is defined as ultrasound-documented gallstones or evidence of a cholecystectomy. Diagnosed gallstone disease or gallbladder surgery is defined as self-reported health care provider gallstone disease diagnosis or history of gallbladder surgery. Data are standardized to the National Health Interview Survey 2020 population with diabetes age 20–74 years, using age categories 20–44, 45–64, and 65–74 years, for ultrasound-detected gallstone disease and age ≥20 years, using age categories 20–44, 45–64, and ≥65 years, for diagnosed gallstone disease. Error bars represent 95% confidence intervals. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin.

SOURCE: National Health and Nutrition Examination Survey (NHANES) III 1988–1994 and NHANES 2017–March 2020 and August 2021–August 2023

Bar graph showing that diagnosed gallstone disease has significantly increased among adults with prediabetes between 1988 and 2023 but prevalences are similar for those with diagnosed and undiagnosed diabetes.

TABLE 1.

Age-Standardized Prevalence and Odds Ratios for Metabolic Dysfunction-Associated Steatotic Liver Disease Diagnosed by Liver Elastography, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2017–March 2020 and August 2021–August 2023

CHARACTERISTICS | DIAGNOSED DIABETES | | UNDIAGNOSED DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 55.7 (52.2–59.1) | 8.3 (6.1–11.2) | 59.2 (52.9–65.2) | 10.4 (7.6–14.2) | 29.1 (27.0–31.3) | 2.5 (2.0–3.1) | 15.5 (11.3–21.0)
Age (years)
20–44 | 63.9 (52.2–74.1) | 10.6 (6.3–18.1) | 74.5 (59.2–85.5) | 17.6 (8.1–37.9) | 28.0 (25.0–31.2) | 2.4 (1.9–3.0) | 13.6 (11.5–16.1)
45–64 | 63.2 (58.9–67.2) | 10.9 (7.3–16.4) | 61.0 (48.8–72.0) | 10.0 (6.1–16.4) | 32.2 (28.6–35.9) | 3.0 (2.1–4.3) | 13.7 (10.0–18.5)
≥65 | 47.5 (43.3–51.8) | 4.4 (2.0–9.5) | 53.9 (45.1–62.6) | 5.8 (2.5–13.4) | 26.9 (23.5–30.6) | 1.7 (0.8–3.6) | 17.5 (9.7–29.6)
Sex
Men | 58.4 (53.7–62.9) | 7.7 (5.3–11.1) | 58.7 (50.6–66.4) | 7.9 (5.3–11.8) | 32.6 (28.9–36.6) | 2.6 (1.9–3.4) | 16.0 (12.0–21.1)
Women | 52.6 (47.8–57.4) | 8.2 (5.5–12.0) | 60.3 (51.1–68.9) | 12.1 (7.9–18.4) | 25.5 (22.9–28.2) | 2.4 (1.7–3.2) | 15.2 (9.6–23.4)
Race/ethnicity
Non-Hispanic White | 61.2 (55.0–67.0) | 10.0 (6.4–15.6) | 64.6 (54.1–73.7) | 11.8 (7.2–19.5) | 30.2 (27.1–33.4) | 2.8 (2.1–3.7) | 16.4 (11.2–23.3)
Non-Hispanic Black | 37.3 (32.2–42.8) | 8.2 (4.8–14.0) | 39.7 (29.0–51.5) | 9.1 (5.4–15.5) | 21.9 (19.1–25.0) | 3.6 (2.3–5.6) | 4.8 (2.4–9.5)^1^
Non-Hispanic Asian | 45.5 (35.9–55.5) | 14.2 (6.8–29.6) | 49.9 (31.3–68.6) | 21.5 (5.2–88.5) | 23.1 (18.9–27.9) | 4.2 (1.9–9.2) | 5.3 (2.9–9.6)
Mexican American | 57.8 (46.5–68.4) | 6.0 (3.4–10.6) | 56.8 (45.5–67.4) | 7.7 (4.5–13.3) | 37.9 (29.2–47.6) | 2.0 (1.2–3.4) | 22.7 (10.9–41.2)^1^
Other Hispanic | 52.8 (45.2–60.3) | 7.8 (4.8–12.6) | 48.8 (33.9–63.9) | 10.7 (4.7–24.1) | 27.9 (22.8–33.6) | 2.2 (1.3–3.5) | 20.1 (11.1–33.5)
Other | 53.7 (40.9–66.1) | ^2^ | 63.6 (33.9–85.7) | ^2^ | 25.5 (16.1–38.0) | ^2^ | ^2^

Diagnosed diabetes is defined as self-reported health care provider diagnosis; undiagnosed diabetes is defined as A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Metabolic dysfunction-associated steatotic liver disease (MASLD) is defined as a controlled attenuation parameter >300 dB/m and alcohol intake of <3 drinks/day for men or <2 drinks/day for women. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–March 2020 and August 2021–August 2023

TABLE 2.

Age-Standardized Prevalence and Odds Ratios for Elevated Liver Stiffness Diagnosed by Liver Elastography, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2017–March 2020 and August 2021–August 2023

CHARACTERISTICS | DIAGNOSED DIABETES | | UNDIAGNOSED DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 27.4 (24.2–30.8) | 7.2 (4.7–11.0) | 23.6 (18.4–29.7) | 6.2 (3.8–10.0) | 10.1 (8.7–11.6) | 2.1 (1.3–3.3) | 7.2 (5.0–10.1)
Age (years)
20–44 | 25.7 (17.4–36.3) | 8.0 (4.4–14.4) | 34.4 (22.1–49.1) | 12.1 (5.7–25.4) | 10.1 (7.5–13.6) | 2.7 (1.5–4.9) | 3.9 (2.5–5.9)
45–64 | 31.5 (26.9–36.4) | 7.8 (4.8–12.9) | 19.9 (13.1–29.0) | 4.2 (2.4–7.3) | 10.2 (8.4–12.2) | 1.9 (1.1–3.3) | 5.5 (3.4–8.9)
≥65 | 24.4 (20.7–28.6) | 3.2 (1.8–5.6) | 24.0 (15.7–34.8) | 3.2 (1.3–7.4) | 10.0 (7.9–12.5) | 1.1 (0.6–2.0) | 9.3 (5.9–14.6)
Sex
Men | 28.2 (24.1–32.6) | 5.1 (3.2–8.1) | 23.1 (17.0–30.6) | 3.9 (2.3–6.6) | 11.5 (9.3–14.1) | 1.5 (0.9–2.7) | 9.6 (5.9–15.3)
Women | 26.3 (22.4–30.7) | 10.1 (5.9–17.2) | 23.2 (16.5–31.6) | 9.5 (4.6–19.8) | 8.9 (7.4–10.7) | 3.0 (1.7–5.2) | 5.9 (3.7–9.3)
Race/ethnicity
Non-Hispanic White | 30.2 (25.5–35.3) | 8.0 (4.8–13.5) | 26.6 (19.5–35.2) | 6.9 (3.8–12.6) | 10.5 (8.7–12.7) | 2.3 (1.3–4.0) | 8.0 (5.4–11.7)
Non-Hispanic Black | 18.8 (15.4–22.8) | 3.4 (1.7–7.1) | 26.6 (18.9–35.9) | 3.9 (1.7–9.0) | 9.8 (7.4–12.9) | 1.6 (0.8–3.2) | 2.5 (1.0–6.1)^2^
Non-Hispanic Asian | 16.9 (9.8–27.5) | ^3^ | 19.4 (10.3–33.5) | ^3^ | 6.0 (3.5–10.1) | ^3^ | ^3^
Mexican American | 29.2 (23.4–35.8) | 9.6 (3.8–24.5) | 22.4 (12.8–36.1) | 7.9 (2.5–24.7) | 15.5 (10.2–23.0) | 4.1 (1.8–9.5) | 6.0 (2.4–14.2)^2^
Other Hispanic | 28.4 (20.2–38.3) | ^3^ | 14.4 (8.2–24.1) | ^3^ | 7.4 (5.1–10.8) | ^3^ | ^3^
Other | 32.4 (22.5–44.2) | ^3^ | 13.6 (5.7–29.2)^2^ | ^3^ | 4.4 (2.2–8.6)^1^ | ^3^ | ^3^

Diagnosed diabetes is defined as self-reported health care provider diagnosis; undiagnosed diabetes is defined as A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Elevated liver stiffness is defined as >8 kPa. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–March 2020 and August 2021–August 2023

TABLE 3.

Prevalence and Odds Ratios for Steatotic Liver Disease and Elevated Liver Stiffness Diagnosed by Liver Elastography Among Adolescents Age 12–19 Years, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2017–March 2020 and August 2021–August 2023

CHARACTERISTICS | STEATOTIC LIVER DISEASE | | | ELEVATED LIVER STIFFNESS
CHARACTERISTICS | Diabetes/Prediabetes | | Normal glycemia | Diabetes/Prediabetes | | Normal glycemia
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 32.3 (27.4–37.5) | 1.7 (1.2–2.5) | 21.3 (17.2–26.1) | 18.2 (13.8–23.6) | 1.1 (0.8–1.6) | 16.1 (12.9–19.9)
Age (years)
12–15 | 29.4 (22.5–37.6) | 2.0 (1.3–3.1) | 17.2 (12.4–23.4) | 14.5 (9.6–21.3) | 1.5 (0.8–2.8) | 10.1 (7.3–13.9)
16–19 | 36.1 (27.6–45.6) | 1.7 (1.0–2.9) | 25.2 (19.3–32.1) | 23.2 (14.8–34.3) | 1.1 (0.6–2.0) | 21.7 (16.0–28.7)
Sex
Male | 29.9 (23.1–37.7) | 1.3 (0.7–2.6) | 24.1 (16.8–33.2) | 21.3 (16.4–27.1) | 1.2 (0.8–1.9) | 18.3 (13.7–23.8)
Female | 36.2 (27.7–45.6) | 2.4 (1.5–4.0) | 18.9 (14.4–24.5) | 13.2 (7.1–23.1) | 0.9 (0.5–1.7) | 14.3 (9.6–20.7)
Race/ethnicity
Non-Hispanic White | 27.2 (20.0–35.7) | 1.8 (1.0–3.2) | 17.3 (12.3–23.9) | 16.2 (10.9–23.4) | 1.2 (0.6–2.3) | 14.3 (9.3–21.3)
Non-Hispanic Black | 30.8 (21.0–42.7) | 1.7 (0.7–4.3) | 20.5 (10.6–35.9)^1^ | 26.2 (16.1–39.7) | 1.2 (0.6–2.4) | 22.6 (16.0–31.0)
Non-Hispanic Asian | 14.8 (7.1–28.3)^1^ | 0.5 (0.1–1.9) | 24.4 (10.8–46.1)^1^ | 20.7 (10.9–35.9) | ^3^ | ^3^
Mexican American | 48.0 (37.3–58.9) | 1.5 (0.6–3.7) | 37.6 (23.5–54.2) | 17.9 (9.2–31.9)^1^ | 1.0 (0.3–3.6) | 17.8 (8.6–33.2)^1^
Other Hispanic | 38.1 (26.1–51.8) | 2.2 (1.0–4.8) | 22.1 (13.2–34.6) | ^3^ | ^3^ | 19.2 (11.9–29.3)
Other | 38.5 (22.9–56.9) | 4.2 (1.2–14.2) | 13.0 (6.1–25.8)^1^ | 18.9 (7.3–40.7)^2^ | 2.3 (0.6–8.2) | 9.3 (3.6–22.2)^2^

Diabetes and prediabetes are combined due to small numbers with diabetes and are defined as self-reported health care provider diagnosis, A1C ≥5.7%, or fasting plasma glucose ≥100 mg/dL. Normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Steatotic liver disease is defined as a controlled attenuation parameter >250 dB/m. Elevated liver stiffness is defined as >6 kPa. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2017–March 2020 and August 2021–August 2023

TABLE 4.

Prevalence and Odds Ratios for Metabolic Dysfunction-Associated Steatotic Liver Disease Among Age-Eligible Medicare Beneficiaries, by Diabetes Status, Age, Sex, Race, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 5.3 (5.2–5.4) | 3.7 (3.6–3.8) | 1.5 (1.5–1.5)
Age (years)
65–69 | 6.7 (6.6–6.8) | 4.4 (4.3–4.5) | 1.6 (1.6–1.6)
70–74 | 5.8 (5.7–5.9) | 3.6 (3.5–3.7) | 1.7 (1.7–1.7)
75–79 | 4.5 (4.4–4.6) | 3.1 (3.0–3.3) | 1.5 (1.4–1.5)
80–84 | 3.2 (3.1–3.3) | 2.9 (2.8–3.1) | 1.1 (1.1–1.2)
≥85 | 1.9 (1.8–2.0) | 2.9 (2.7–3.1) | 0.7 (0.6–0.7)
Sex
Men | 4.4 (4.3–4.5) | 3.5 (3.4–3.6) | 1.3 (1.3–1.3)
Women | 5.6 (5.5–5.7) | 3.8 (3.7–3.9) | 1.5 (1.5–1.6)
Race
White | 5.4 (5.3–5.4) | 3.3 (3.2–3.4) | 1.5 (1.5–1.5)
Black | 2.6 (2.5–2.7) | 4.3 (4.2–4.4) | 0.8 (0.8–0.9)
Other | 5.4 (5.3–5.6) | 3.7 (3.6–3.8) | 1.3 (1.3–1.4)
Region
Northeast | 5.2 (5.1–5.4) | 3.6 (3.5–3.7) | 1.5 (1.5–1.6)
Midwest | 4.6 (4.5–4.7) | 3.6 (3.5–3.6) | 1.3 (1.3–1.4)
South | 5.1 (5.0–5.2) | 3.4 (3.3–3.5) | 1.6 (1.5–1.6)
West | 5.1 (5.0–5.2) | 4.2 (4.1–4.3) | 1.3 (1.2–1.3)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Metabolic dysfunction-associated steatotic liver disease (MASLD) is defined by ICD-10-CM codes K75.81 or K76.0 in any position on a claim. Beneficiaries were age ≥65 years with any Parts A or B enrollment or Health Maintenance Organization enrollment during the year. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race, and region.

SOURCE: Centers for Medicare and Medicaid Services 5% Denominator and Claims Files 2022

TABLE 5.

Age-Standardized Prevalence and Odds Ratios for Metabolic Dysfunction-Associated Steatotic Liver Disease Among Medicaid Beneficiaries, by Diabetes Status, Age, Sex, Race/Ethnicity, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 6.0 (6.0–6.1) | 3.8 (3.7–3.8) | 1.7 (1.7–1.7)
Age (years)
19–34 | 6.6 (6.5–6.6) | 8.0 (7.9–8.1) | 0.9 (0.9–0.9)
35–44 | 6.5 (6.5–6.6) | 4.8 (4.8–4.9) | 1.4 (1.4–1.4)
45–54 | 5.9 (5.9–6.0) | 3.4 (3.3–3.4) | 1.8 (1.8–1.8)
55–64 | 4.5 (4.5–4.6) | 3.0 (3.0–3.0) | 1.6 (1.5–1.6)
Sex
Men | 6.3 (6.3–6.4) | 4.0 (3.9–4.0) | 1.7 (1.7–1.7)
Women | 4.6 (4.6–4.6) | 3.5 (3.5–3.6) | 1.3 (1.3–1.4)
Race/ethnicity
Non-Hispanic White | 6.1 (6.1–6.1) | 3.3 (3.2–3.3) | 1.5 (1.5–1.6)
Non-Hispanic Black | 3.2 (3.2–3.2) | 3.0 (3.0–3.0) | 0.9 (0.8–0.9)
Non-Hispanic Asian | 5.7 (5.6–5.8) | 3.9 (3.8–3.9) | 2.0 (2.0–2.0)
Non-Hispanic American Indian/Alaska Native | 4.9 (4.8–5.1) | 3.2 (3.1–3.2) | 1.6 (1.5–1.6)
Non-Hispanic Hawaiian/Pacific Islander | 5.1 (4.9–5.3) | 3.5 (3.5–3.5) | 1.7 (1.6–1.7)
Hispanic, all races | 6.9 (6.9–7.0) | 4.1 (4.1–4.2) | 2.1 (2.1–2.1)
Multiracial/unknown | 5.6 (5.5–5.6) | 3.9 (3.9–4.0) | 1.5 (1.5–1.5)
Region
Northeast | 6.2 (6.1–6.2) | 3.8 (3.7–3.8) | 1.9 (1.9–1.9)
Midwest | 5.0 (4.9–5.0) | 3.4 (3.3–3.4) | 1.4 (1.4–1.4)
South | 5.1 (5.1–5.2) | 4.5 (4.5–4.6) | 1.2 (1.2–1.2)
West | 6.0 (5.9–6.0) | 3.8 (3.7–3.8) | 1.7 (1.7–1.7)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Metabolic dysfunction-associated steatotic liver disease (MASLD) is defined by ICD-10-CM codes K75.81 or K76.0 in any position on a claim. Beneficiaries were age 19–64 years with any enrollment during the year. Data are standardized to the Medicaid 2019 population with diabetes age 19–64 years, using age categories 19–34, 35–44, 45–54, and 55–64 years. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race/ethnicity, and region.

SOURCE: Centers for Medicare and Medicaid Services Denominator and Claims Files, 2022

TABLE 6.

Prevalence and Incidence and Relative Risk of Diabetes by HCV Status

POPULATION, YEARS, DESIGN (REF.) | HCV STATUS (SAMPLE SIZE; PREVALENCE) | DIABETES | ADJUSTED RR FOR DIABETES (95% CI)
Meta-analyses
25 studies of 233,683 patients, 2010–2019 (44) | [underlined: Status]: Decompensation HCV cirrhosis Chronic HCV Clearance Negative | | [underlined: OR]: 3.84 (2.01–7.34) 3.37 (2.33–4.89) 1.73 (1.28–2.34) 1.21 (0.75–1.96) 1.0
21 studies of 22,432 East Asian patients, 1996–2018 (45) | [underlined: Status]: Positive Negative | [underlined: Prevalence (% [95% CI])]: 19.0 (15.6–22.9) 12.5 (8.3–18.3) | [underlined: OR]: 1.58 (1.28–1.94) 1.0
31 studies, 1996–2014 (46) | [underlined: Status]: Positive (n=61,843) Negative (n=202,130) | [underlined: Prevalence (% [95% CI])]: 15 (13–18) 10 (6–15) | [underlined: OR]: 1.58 (1.30–1.86) 1.0
33 studies, through 2016 (47) | [underlined: Status]: HCV cirrhosis (n=207) Chronic HCV (n=1,046) Negative | | [underlined: OR]: 6.82 (4.50–10.49) 2.12 (1.60–2.82) 1.0
Population-Based Studies
Western U.S. participants in major health system, 2013–2015, cross-sectional (48) | [underlined: Status]: Positive (n=23,492; 0.86%) Negative (n=2.7 million) | [underlined: Prevalence (%)]: 18.7 8.9 (p<0.0001)
Swedish nationwide population-based register study, 2013 (49) | [underlined: Status]: Positive (n=34,633; 0.36%) Negative (n=171,338 matched general population controls) | [underlined: Prevalence (%)]: 10.6 5.5 (p<0.01)
British Columbia, Canada, 1990–2015, cohort study of people tested for HCV (50) | [underlined: Status (overall)]: Positive (n=61,570) Negative (n=785,451) | [underlined: Incidence (per 1,000 person-years [95% CI])]: 5.85 (5.68–6.03) 5.40 (5.34–5.46) (p<0.001)
British Columbia, Canada, 1990–2015, cohort study of people tested for HCV (50) | [underlined: Propensity-score matched subset]: Positive (n=58,592) Negative (n=58,592) | | [underlined: Adjusted HR]: 2.32 (2.20–2.45) 1.0
Koreans who underwent health check-ups, age 40–79 years, 2002–2013, national cohort study (51) | [underlined: Status]: Positive (n=1,040) Negative (n=420,209) | [underlined: Cumulative incidence (%)]: 32.9 18.3 | [underlined: Adjusted HR]: 1.68 (1.52–1.86) 1.0
Mexican Americans in Southern Texas, 2004 (52) | [underlined: Status]: Positive (n=30; 2.3%) Negative (n=1,301) | | [underlined: Adjusted OR]: 0.20 (0.05–0.77) 1.0
Scottish national population-based register study, 2011 (53) | [underlined: Status]: Positive (n=21,929) Negative (n=65,074 matched general population controls) | [underlined: Prevalence (%)]: 2.9 2.7

CI, confidence interval; HCV, hepatitis C virus; HR, hazard ratio; OR, odds ratio; RR, relative risk.

SOURCE: References are listed within the table.

TABLE 7.

Age-Standardized Prevalence and Odds Ratios of Positive Serum Antibody to Hepatitis C Virus (HCV Ab+), by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2011–March 2020

CHARACTERISTICS | DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 2.0 (1.5–2.7) | 0.9 (0.5–1.7) | 2.1 (1.3–3.4) | 1.0 (0.5–2.0) | 1.9 (1.3–3.0)
Age (years)
20–44 | ^3^ | ^3^ | 0.8 (0.5–1.5) | 0.9 (0.4–2.0) | 0.7 (0.4–1.5)^1^
45–64 | 3.4 (2.4–4.8) | 0.8 (0.4–1.6) | 3.7 (2.0–6.6) | 0.9 (0.4–2.0) | 3.8 (2.3–6.3)
≥65 | 1.4 (0.8–2.5) | ^3^ | 1.1 (0.6–2.0)^1^ | ^3^ | ^3^
Sex
Men | 2.7 (2.0–3.8) | 0.8 (0.3–1.9) | 2.2 (1.4–3.4) | 0.7 (0.3–1.4) | 3.3 (1.9–5.7)
Women | 1.2 (0.7–1.9) | 0.8 (0.4–1.7) | 2.0 (0.9–4.1)^1^ | 1.7 (0.7–4.0) | 1.2 (0.6–2.2)^1^
Race/ethnicity
Non-Hispanic White | 2.0 (1.3–3.1) | 1.0 (0.4–2.3) | 2.1 (1.1–4.0)^1^ | 1.1 (0.5–2.6) | 1.9 (1.1–3.3)
Non-Hispanic Black | 4.2 (2.8–6.4) | 0.9 (0.5–1.6) | 3.5 (2.4–5.2) | 0.6 (0.3–1.1) | 4.3 (2.3–7.8)^1^
Non-Hispanic Asian | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Mexican American | 1.2 (0.6–2.5)^1^ | ^3^ | 1.4 (0.6–3.2)^2^ | ^3^ | ^3^
Other Hispanic | 1.8 (0.8–4.0)^2^ | 1.4 (0.4–4.8) | ^3^ | ^3^ | 1.1 (0.5–2.3)^1^
Other | 1.8 (0.7–4.8)^2^ | ^3^ | ^3^ | ^3^ | ^3^

Diabetes is defined as self-reported health care provider diagnosis or A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2011–March 2020

TABLE 8.

Age-Standardized Prevalence and Odds Ratios of Presence of Serum Hepatitis C Virus RNA, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2011–March 2020

CHARACTERISTICS | DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 1.0 (0.7–1.3) | 0.6 (0.3–1.2) | 0.9 (0.6–1.3) | 0.6 (0.3–1.1) | 1.4 (0.8–2.3)
Age (years)
20–44 | ^3^ | ^3^ | 0.6 (0.3–1.3)^1^ | 1.4 (0.4–4.7) | 0.3 (0.1–0.8)^2^
45–64 | 1.6 (1.1–2.5) | 0.5 (0.3–1.1) | 1.3 (0.9–2.0) | 0.5 (0.2–0.9) | 2.7 (1.5–4.7)
≥65 | 0.5 (0.3–0.7) | ^3^ | 0.6 (0.2–1.3)^2^ | ^3^ | ^3^
Sex
Men | 1.6 (1.1–2.2) | 0.6 (0.2–1.3) | 1.4 (0.8–2.3) | 0.5 (0.2–1.1) | 2.9 (1.7–4.9)
Women | 0.3 (0.2–0.6) | ^3^ | 0.4 (0.2–0.7) | ^3^ | ^3^
Race/ethnicity
Non-Hispanic White | 1.0 (0.6–1.5) | 0.8 (0.3–2.2) | 0.9 (0.5–1.5) | 0.8 (0.3–2.0) | 1.2 (0.6–2.5)1
Non-Hispanic Black | 2.6 (1.6–4.1) | 0.8 (0.4–1.5) | 1.9 (1.3–2.7) | 0.6 (0.3–1.1) | 3.3 (1.7–6.1)^1^
Non-Hispanic Asian | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Mexican American | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Other Hispanic | ^3^ | ^3^ | 0.4 (0.2–0.8)^2^ | ^3^ | ^3^
Other | ^3^ | ^3^ | ^3^ | ^3^ | ^3^

Diabetes is defined as self-reported health care provider diagnosis or A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio; RNA, ribonucleic acid.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2011–March 2020

TABLE 9.

Age-Standardized Prevalence and Odds Ratios of Positive Serum Antibody to Hepatitis B Core Antigen (HBcAb+), by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2011–March 2020

CHARACTERISTICS | DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 6.8 (5.8–7.8) | 0.9 (0.7–1.1) | 6.5 (5.5–7.7) | 1.1 (0.9–1.5) | 5.3 (4.0–6.9)
Age (years)
20–44 | 2.3 (1.4–3.8) | 0.7 (0.4–1.3) | 2.4 (1.8–3.1) | 1.0 (0.7–1.4) | 2.0 (1.5–2.6)
45–64 | 7.2 (5.9–8.6) | 1.2 (0.8–1.7) | 7.5 (6.1–9.3) | 1.3 (0.9–2.0) | 5.6 (4.1–7.6)
≥65 | 7.6 (6.2–9.2) | 1.3 (0.8–2.3) | 6.7 (5.4–8.4) | 1.2 (0.7–2.0) | 5.8 (3.7–9.1)
Sex
Men | 7.5 (6.3–8.9) | 0.9 (0.6–1.3) | 7.2 (6.0–8.6) | 0.9 (0.7–1.2) | 7.4 (5.0–10.8)
Women | 5.9 (4.7–7.4) | 1.5 (1.1–2.1) | 6.0 (4.6–7.7) | 1.6 (1.1–2.4) | 4.1 (2.8–5.9)
Race/ethnicity
Non-Hispanic White | 2.6 (1.9–3.6) | 0.8 (0.5–1.4) | 4.1 (3.0–5.6) | 1.3 (0.8–2.4) | 2.9 (1.7–5.0)
Non-Hispanic Black | 15.1 (12.8–17.7) | 1.1 (0.8–1.5) | 14.6 (12.2–17.4) | 1.2 (0.9–1.7) | 13.9 (8.9–21.2)
Non-Hispanic Asian | 34.0 (28.9–39.5) | 1.0 (0.6–1.5) | 34.5 (30.4–38.7) | 1.1 (0.8–1.6) | 32.0 (22.7–42.8)
Mexican American | 3.7 (2.6–5.3) | 0.4 (0.2–0.9) | 4.1 (2.5–6.5) | 0.4 (0.2–1.2) | 7.8 (2.8–19.9)^2^
Other Hispanic | 12.9 (10.1–16.3) | 1.4 (0.7–2.8) | 10.8 (7.2–15.9) | 1.2 (0.6–2.7) | 15.6 (8.8–26.2)
Other | 3.6 (1.5–8.1)^2^ | ^3^ | 3.1 (1.7–5.7)^1^ | ^3^ | ^3^

Diabetes is defined as self-reported health care provider diagnosis or A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2011–March 2020

TABLE 10.

Age-Standardized Prevalence and Odds Ratios of Positive Serum Hepatitis B Virus Surface Antigen (HBsAg+), by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2011–March 2020

CHARACTERISTICS | DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 0.4 (0.3–0.7) | 0.6 (0.3–1.4) | 0.2 (0.2–0.3) | 0.6 (0.3–1.1) | 0.8 (0.3–2.2)^2^
Age (years)
20–44 | ^3^ | ^3^ | 0.4 (0.2–0.6) | 1.0 (0.5–2.1) | 0.3 (0.2–0.5)
45–64 | 0.5 (0.3–0.8) | 1.3 (0.5–3.4) | 0.4 (0.2–0.7) | 1.1 (0.5–2.6) | 0.3 (0.2–0.7)^1^
≥65 | 0.4 (0.2–0.8)^1^ | ^3^ | 0.1 (0.0–0.2)^1^ | ^3^ | ^3^
Sex
Men | 0.5 (0.3–0.9) | 1.5 (0.6–3.5) | 0.2 (0.1–0.3) | 0.7 (0.3–1.6) | 0.4 (0.2–0.9)^2^
Women | 0.3 (0.2–0.6)^1^ | ^3^ | 0.3 (0.2–0.5) | ^3^ | ^3^
Race/ethnicity
Non-Hispanic White | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Non-Hispanic Black | 0.7 (0.3–1.6)^1^ | ^3^ | 0.5 (0.3–0.9) | ^3^ | ^3^
Non-Hispanic Asian | 4.7 (3.1–7.1) | ^3^ | 2.2 (1.4–3.5) | ^3^ | ^3^
Mexican American | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Other Hispanic | ^3^ | ^3^ | ^3^ | ^3^ | ^3^
Other | ^3^ | ^3^ | ^3^ | ^3^ | ^3^

Diabetes is defined as self-reported health care provider diagnosis or A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2011–March 2020

TABLE 11.

Prevalence / Incidence of Diabetes by Cirrhosis Status

POPULATION, YEARS, DESIGN (REF.) | SAMPLE SIZE | DIABETES (% [95% CI])
Meta-analysis
45 studies, 1990–2017 (64) | | [underlined: Prevalence]: Overall: 31 (28–34) Cirrhosis type: NAFLD: 56 (31–79) Cryptogenic: 51 (42–60) HCV: 32 (29–35) Alcohol: 27 (22–33) HBV: 22 (18–27) Cholestatic: 7 (3–16)
Population-Based Studies
All cirrhosis cases within a Swedish county, 2011–2018, retrospective cohort study (65) | 598 | [underlined: Prevalence]: Overall: 29 Cirrhosis type: NAFLD: 53 Cryptogenic: 43 PBC: 29 Alcohol: 26 Other: 24 HCV: 21 AIH: 13
All patients hospitalized for cirrhosis in Queensland, Australia, 2008–2016, retrospective cohort study (66) | 10,254 | [underlined: Prevalence]: Overall: 19 Cirrhosis type: NAFLD: 53 Inflammatory, unspecified: 34 Cryptogenic: 27 AIH: 19 PSC: 19 HBV: 16 Hemochromatosis: 15 Alcohol: 14 HCV: 11
All patients hospitalized for cirrhosis in Queensland, Australia, 2008–2017, retrospective cohort study (67) | 8,631 | Prevalence: 19 Incidence: 11
Spanish patients with alcoholic or HCV cirrhosis in a hepatocellular carcinoma surveillance program, 1992–2014 (68) | 982 | [underlined: Prevalence]: Overall: 25 Cirrhosis type: Alcohol: 29 HCV: 17

AIH, autoimmune hepatitis; CI, confidence interval; HBV, hepatitis B virus; HCV, hepatitis C virus; NAFLD, nonalcoholic fatty liver disease; PBC, primary biliary cholangitis; PSC, primary sclerosing cholangitis.

SOURCE: References are listed within the table.

TABLE 12.

Prevalence and Odds Ratios for Cirrhosis, by Diabetes Status, Age, Sex, Race, and Region Among Age-Eligible Medicare Beneficiaries, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 2.4 (2.3–2.4) | 4.0 (3.8–4.1) | 0.6 (0.6–0.6)
Age (years)
65–69 | 2.8 (2.7–2.9) | 4.7 (4.5–4.9) | 0.6 (0.6–0.6)
70–74 | 2.4 (2.4–2.5) | 4.0 (3.8–4.2) | 0.6 (0.6–0.6)
75–79 | 2.1 (2.0–2.2) | 3.7 (3.5–3.9) | 0.6 (0.6–0.6)
80–84 | 1.8 (1.7–1.9) | 3.3 (3.1–3.6) | 0.5 (0.5–0.6)
≥85 | 1.2 (1.1–1.3) | 2.7 (2.4–2.9) | 0.5 (0.4–0.5)
Sex
Men | 2.3 (2.3–2.4) | 3.6 (3.5–3.8) | 0.7 (0.6–0.7)
Women | 2.2 (2.1–2.2) | 4.2 (4.1–4.4) | 0.5 (0.5–0.5)
Race
White | 2.3 (2.3–2.4) | 2.7 (2.6–2.8) | 0.6 (0.6–0.6)
Black | 1.4 (1.3–1.5) | 4.4 (4.2–4.5) | 0.5 (0.5–0.6)
Other | 2.6 (2.5–2.7) | 4.1 (3.9–4.2) | 0.6 (0.6–0.6)
Region
Northeast | 2.1 (2.0–2.2) | 4.0 (3.9–4.2) | 0.6 (0.5–0.6)
Midwest | 2.2 (2.1–2.2) | 3.7 (3.6–3.9) | 0.5 (0.5–0.6)
South | 2.3 (2.2–2.4) | 3.9 (3.8–4.0) | 0.6 (0.6–0.6)
West | 2.5 (2.4–2.5) | 4.2 (4.0–4.3) | 0.6 (0.6–0.6)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Cirrhosis is defined by ICD-10-CM codes K70.3, K71.7, or K74.3–K74.6 in any position on a claim. Beneficiaries were age ≥65 years with any Parts A or B enrollment or Health Maintenance Organization enrollment during the year. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race, and region.

SOURCE: Centers for Medicare and Medicaid Services 5% Denominator and Claims Files, 2022

TABLE 13.

Age-Standardized Prevalence and Odds Ratios for Cirrhosis Among Medicaid Beneficiaries, by Diabetes Status, Age, Sex, Race/Ethnicity, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 2.0 (2.0–2.0) | 2.7 (2.6–2.7) | 0.8 (0.7–0.8)
Age (years)
19–34 | 0.6 (0.5–0.6) | 6.6 (6.3–6.8) | 0.1 (0.1–0.1)
35–44 | 1.3 (1.2–1.3) | 3.6 (3.6–3.7) | 0.4 (0.3–0.4)
45–54 | 2.0 (2.0–2.1) | 2.7 (2.6–2.7) | 0.8 (0.8–0.8)
55–64 | 2.4 (2.4–2.5) | 2.3 (2.2–2.3) | 1.1 (1.1–1.1)
Sex
Men | 1.6 (1.6–1.6) | 2.9 (2.8–2.9) | 0.6 (0.6–0.6)
Women | 2.2 (2.2–2.3) | 2.4 (2.4–2.4) | 0.9 (0.9–0.9)
Race/ethnicity
Non-Hispanic White | 2.3 (2.3–2.3) | 2.2 (2.2–2.2) | 0.9 (0.9–0.9)
Non-Hispanic Black | 1.0 (1.0–1.0) | 2.9 (2.8–3.0) | 0.4 (0.4–0.5)
Non-Hispanic Asian | 0.9 (0.9–1.0) | 2.2 (2.2–2.3) | 0.3 (0.3–0.3)
Non-Hispanic American Indian/Alaska Native | 3.5 (3.4–3.6) | 2.4 (2.4–2.4) | 1.6 (1.6–1.7)
Non-Hispanic Hawaiian/Pacific Islander | 1.1 (1.0–1.2) | 2.8 (2.7–2.8) | 0.5 (0.4–0.5)
Hispanic, all races | 2.2 (2.2–2.2) | 2.7 (2.6–2.7) | 0.8 (0.8–0.8)
Multiracial/unknown | 1.7 (1.7–1.8) | 2.7 (2.6–2.7) | 0.7 (0.6–0.7)
Region
Northeast | 1.6 (1.6–1.6) | 2.3 (2.3–2.4) | 0.7 (0.6–0.7)
Midwest | 1.7 (1.7–1.8) | 2.5 (2.4–2.5) | 0.8 (0.7–0.8)
South | 2.0 (2.0–2.1) | 2.8 (2.8–2.9) | 0.7 (0.7–0.7)
West | 2.1 (2.1–2.1) | 2.7 (2.7–2.7) | 0.8 (0.8–0.8)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Cirrhosis is defined by ICD-10-CM codes K70.3, K71.7, or K74.3–K74.6 in any position on a claim. Beneficiaries were age 19–64 years with any enrollment during the year. Data are standardized to the Medicaid 2019 population with diabetes age 19–64 years, using age categories 19–34, 35–44, 45–54, and 55–64 years. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race/ethnicity, and region.

SOURCE: Centers for Medicare and Medicaid Services Denominator and Claims Files, 2022

TABLE 14.

Characteristics of Adult Patients at Listing for Liver Transplantation and at Transplantation, by Diabetes Status, U.S., 2014–2023

CHARACTERISTICS | N | DIABETES | NO DIABETES | P-VALUE*
At Listing
N | | 31,074 | 73,131
Age (years; mean [SD]) | 104,205 | 59.8 (8.4) | 54.2 (11.7) | <0.001
Male (%) | 65,683 | 64.0 | 62.6 | <0.001
Ethnicity (%) | | | | <0.001
White | 72,623 | 65.8 | 71.3
Black | 7,834 | 7.1 | 7.7
Hispanic | 17,562 | 20.8 | 15.2
Asian | 4,317 | 4.5 | 4.0
Other (non-missing) | 1,869 | 1.7 | 1.8
Highest education level (≥associate degree; %) | 28,364 | 25.8 | 29.1 | <0.001
Functional status (needs assistance; %) | 74,795 | 73.8 | 72.8 | <0.001
Liver disease diagnoses (%) ^†^
Alcohol-associated liver disease | 35,020 | 21.7 | 38.6 | <0.001
MASLD | 23,021 | 43.9 | 12.8 | <0.001
Hepatocellular carcinoma | 21,665 | 26.3 | 18.4 | <0.001
Hepatitis C | 20,535 | 18.1 | 20.4 | <0.001
Autoimmune or cholestatic | 10,850 | 6.1 | 12.2 | <0.001
Other causes of cirrhosis | 5,742 | 5.8 | 5.4 | 0.003
Hepatitis B | 2,504 | 2.2 | 2.5 | 0.011
BMI (kg/m^2^; mean [SD]) | 103,845 | 30.5 (6.1) | 28.5 (6.1) | <0.001
MELD score (beginning 2/28/02, mean [SD]) | 104,201 | 17.1 (8.4) | 19.6 (9.7) | <0.001
Blood type O (%) | 48,392 | 46.4 | 46.4 | 0.95
At Transplant
N | | 19,075 | 46,604
Time on waiting list (days; mean [SD]) | 65,679 | 198 (270) | 157 (261) | <0.001
Functional status (needs assistance; %) | 53,975 | 85.4 | 84.1 | <0.001
Cold ischemia time (minutes; mean [SD]) | 64,275 | 6.0 (2.5) | 5.9 (2.5) | <0.001
MELD score (beginning 2/28/02, mean [SD]) | 65,679 | 18.1 (8.8) | 21.3 (10.0) | <0.001
Donor Characteristics
Age (years; mean [SD]) | 65,674 | 42.1 (15.8) | 41.0 (15.5) | <0.001
Male (%) | 39,644 | 60.9 | 60.2 | 0.087
Ethnicity (%) | | | | 0.49
White | 42,370 | 64.4 | 64.6
Black | 11,635 | 18.0 | 17.6
Hispanic | 9,161 | 13.7 | 14.1
Asian | 1,676 | 2.6 | 2.5
Other (non-missing) | 837 | 1.3 | 1.3

BMI, body mass index; MASLD, metabolic dysfunction-associated steatotic liver disease; MELD, Model for End-Stage Liver Disease; SD, standard deviation.

* From a t-test for means or χ^2^ test for percentages

^†^ Because patients may have more than one liver disease, the percentages are not mutually exclusive and add to greater than 100%.

SOURCE: Standard Analysis File of the Scientific Registry of Transplant Recipients 2014–2023

TABLE 15.

Prevalence and Odds Ratios for Liver Transplantation Among Age-Eligible Medicare Beneficiaries, by Diabetes Status, Age, Sex, Race, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 0.2 (0.2–0.2) | 3.9 (3.3–4.5) | 0.1 (0.0–0.1)
Age (years)
65–69 | 0.3 (0.3–0.4) | 5.8 (5.2–6.5) | 0.1 (0.1–0.1)
70–74 | 0.2 (0.2–0.2) | 4.3 (3.7–5.0) | 0.1 (0.0–0.1)
75–79 | 0.1 (0.1–0.1) | 4.4 (3.4–5.6) | 0.0 (0.0–0.0)
80–84 | 0.1 (0.1–0.1) | 4.2 (2.8–6.4) | 0.0 (0.0–0.0)
≥85 | 0.0 (0.0–0.0) | 8.3 (3.8–18.1) | 0.0 (0.0–0.0)
Sex
Men | 0.3 (0.2–0.3) | 4.9 (4.4–5.6) | 0.1 (0.0–0.1)
Women | 0.1 (0.1–0.1) | 4.8 (4.1–5.7) | 0.0 (0.0–0.0)
Race
White | 0.2 (0.2–0.2) | 3.0 (2.5–3.5) | 0.0 (0.0–0.0)
Black | 0.1 (0.1–0.1) | 5.8 (5.1–6.7) | 0.0 (0.0–0.0)
Other | 0.3 (0.2–0.3) | 4.9 (4.2–5.6) | 0.0 (0.0–0.1)
Region
Northeast | 0.2 (0.2–0.2) | 5.1 (4.5–5.9) | 0.0 (0.0–0.0)
Midwest | 0.2 (0.2–0.2) | 5.1 (4.4–5.8) | 0.0 (0.0–0.0)
South | 0.2 (0.2–0.2) | 4.6 (4.0–5.3) | 0.0 (0.0–0.0)
West | 0.2 (0.2–0.2) | 5.5 (4.8–6.4) | 0.0 (0.0–0.0)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Liver transplantation is defined by ICD-10-CM code Z94.4, ICD-10-PCS codes 0FY00Z0, 0FY00Z1, or 0FY00Z2, or CPT code 47135 in any position on a claim. Beneficiaries were age ≥65 years with any Parts A or B enrollment or Health Maintenance Organization enrollment during the year. CI, confidence interval; CPT, Current Procedural Terminology; ICD-10-CM/PCS, International Classification of Diseases, Tenth Revision, Clinical Modification/Procedure Coding System; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race, and region.

SOURCE: Centers for Medicare and Medicaid Services 5% Denominator and Claims Files, 2022

TABLE 16.

Age-Standardized Prevalence and Odds Ratios for Liver Transplantation Among Medicaid Beneficiaries, by Diabetes Status, Age, Sex, Race/Ethnicity, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 0.1 (0.1–0.2) | 3.1 (2.8–3.3) | 0.0 (0.0–0.1)
Age (years)
19–34 | 0.1 (0.1–0.1) | 7.1 (6.4–7.8) | 0.0 (0.0–0.0)
35–44 | 0.1 (0.1–0.1) | 4.3 (3.9–4.7) | 0.0 (0.0–0.0)
45–54 | 0.1 (0.1–0.1) | 3.2 (3.0–3.4) | 0.0 (0.0–0.0)
55–64 | 0.2 (0.2–0.2) | 3.3 (3.1–3.4) | 0.1 (0.1–0.1)
Sex
Men | 0.1 (0.1–0.1) | 3.3 (3.1–3.5) | 0.0 (0.0–0.0)
Women | 0.2 (0.2–0.2) | 3.7 (3.5–3.9) | 0.0 (0.0–0.1)
Race/ethnicity
Non-Hispanic White | 0.1 (0.1–0.2) | 2.4 (2.3–2.6) | 0.0 (0.0–0.0)
Non-Hispanic Black | 0.1 (0.1–0.1) | 4.0 (3.8–4.2) | 0.0 (0.0–0.0)
Non-Hispanic Asian | 0.1 (0.1–0.2) | 3.7 (3.4–4.0) | 0.0 (0.0–0.0)
Non-Hispanic American Indian/Alaska Native | 0.1 (0.1–0.1) | 4.8 (4.5–5.2) | 0.1 (0.0–0.1)
Non-Hispanic Hawaiian/Pacific Islander | 0.1 (0.1–0.1) | 3.6 (3.4–3.8) | 0.0 (0.0–0.0)
Hispanic, all races | 0.2 (0.2–0.2) | 3.4 (3.2–3.6) | 0.1 (0.0–0.1)
Multiracial/unknown | 0.1 (0.1–0.1) | 3.7 (3.5–4.0) | 0.0 (0.0–0.0)
Region
Northeast | 0.1 (0.1–0.1) | 3.1 (2.9–3.2) | 0.0 (0.0–0.0)
Midwest | 0.1 (0.1–0.1) | 3.4 (3.3–3.6) | 0.0 (0.0–0.0)
South | 0.1 (0.1–0.1) | 3.6 (3.4–3.8) | 0.0 (0.0–0.0)
West | 0.1 (0.1–0.1) | 3.8 (3.6–4.1) | 0.0 (0.0–0.0)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Liver transplantation is defined by ICD-10-CM code Z94.4, ICD-10-PCS codes 0FY00Z0, 0FY00Z1, or 0FY00Z2, or CPT code 47135 in any position on a claim. Beneficiaries were age 19–64 years with any enrollment during the year. Data are standardized to the Medicaid 2019 population with diabetes age 19–64 years, using age categories 19–34, 35–44, 45–54, and 55–64 years. CI, confidence interval; CPT, Current Procedural Terminology; ICD-10-CM/PCS, International Classification of Diseases, Tenth Revision, Clinical Modification/Procedure Coding System; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, and race/ethnicity, and region.

SOURCE: Centers for Medicare and Medicaid Services Denominator and Claims Files, 2022

TABLE 17.

Prevalence / Incidence and Relative Risk of Ultrasound-Diagnosed Gallstone Disease, by Diabetes Status

POPULATION, YEARS (REF.) | SAMPLE SIZE | DIABETES STATUS | GALLSTONE DISEASE (%) | ADJUSTED OR (95% CI)
U.S. Studies of Gallstone Disease Prevalence
NHANES III, 1988–1994 (71) | Men, n=5,257 | Diagnosed diabetes No diabetes | | 1.54 (1.03–2.30) 1.0
NHANES III, 1988–1994 (71) | Women, n=5,384 | Diagnosed diabetes No diabetes | | 1.63 (1.12–2.36) 1.0
NHANES III, 1988–1994 (77) | [underlined: Men]: n=111 n=280 n=2,281 | [underlined: Fasting plasma glucose (mg/dL)]: ≥126 ≥110–<126 <110 | . 24.8 10.4 6.9 | . 2.11 (0.76–5.85) 0.68 (0.29–1.62) 1.0
NHANES III, 1988–1994 (77) | [underlined: Women]: n=109 n=199 n=2,673 | [underlined: Fasting plasma glucose (mg/dL)]: ≥126 ≥110–<126 <110 | . 42.6 30.1 14.6 | . 1.91 (1.29–2.83) 1.17 (0.70–1.95) 1.0
South Texas Mexican American adults age 15–74 yrs, 1985–1986 (78) | Men, n=300 | Diabetes* No diabetes | | 0.5 (0.1–2.4) 1.0
South Texas Mexican American adults age 15–74 yrs, 1985–1986 (78) | Women, n=699 | Diabetes* No diabetes | | 2.0 (1.1–3.6) 1.0
Native American adults age ≥47 yrs (Strong Heart Study), 1993–1995 (79) | Men, n=1,251 | Diabetes IGT Normal OGTT | | 1.29 (0.96–1.72) 1.32 (0.89–1.96) 1.0
Native American adults age ≥47 yrs (Strong Heart Study), 1993–1995 (79) | Women, n=2,045 | Diabetes IGT Normal OGTT | | 1.43 (1.14–1.80) 0.96 (0.71–1.29) 1.0
Recent Non-U.S. Studies of Gallstone Disease Prevalence
Danish adults age 30–60 yrs, 1993–1994 (87) | 2,650 | Fasting glucose (per 1 mmol/L) | 15.9 | 1.14 (1.05–1.24)
Chinese adults age ≥18 yrs, 2011 (88) | 5,454 | [underlined: Diabetes history]: Present Absent | 15 | . 1.76 (1.31–2.37) 1.0
Chinese adults, 2017 (89) | 10.9 million | [underlined: Fasting glucose (mmol/L)]: ≥7 <7 | 3.6 | . 1.41 (1.39–1.43) 1.0
Chilean adults age 38–74 yrs, 2015–2019 (90) | Men, n=4,030 | All Diabetes No diabetes | 17.1 | . 1.14 (0.96–1.35) 1.0
Chilean adults age 38–74 yrs, 2015–2019 (90) | Women, n=4,918 | All Diabetes No diabetes | 40.4 | . 1.17 (1.08–1.27) 1.0
Studies of Gallstone Disease Incidence
Italian adults age 30–69 yrs, 1985–1993 (91) | 1,962 | All Diabetes No diabetes | | . 2.62 (1.21–5.66) 1.0
Italian adults age 30–79 yrs, 1985–1998 (92) | Men, n=5,428 | [underlined: Gallstones]: Diabetes No diabetes [underlined: Cholecystectomy]: Diabetes No diabetes | | . 1.75 (1.04–2.96) 1.0 . 2.72 (0.89–8.33) 1.0
Italian adults age 30–79 yrs, 1985–1998 (92) | Women, n=4,089 | [underlined: Gallstones]: Diabetes No diabetes [underlined: Cholecystectomy]: Diabetes No diabetes | | . 1.10 (0.58–2.09) 1.0 . 1.00 (0.22–4.49) 1.0
Taiwanese adults, 2002–2007 (93) | 1,296 | [underlined: Fasting plasma glucose (mg/dL)]: ≥126 110–125 <110 | 0.63 per year | . 1.68 (1.10–3.87) 1.22 (0.49–2.31) 1.0

A conversion formula for glucose values is available in the Conversions section. CI, confidence interval; IGT, impaired glucose tolerance; OGTT, oral glucose tolerance test; OR, odds ratio.

* Diabetes is defined as diagnosed and treated or fasting whole blood glucose ≥120 mg/dL on repeat testing.

SOURCE: References are listed within the table.

TABLE 18.

Age-Standardized Prevalence and Odds Ratios for Diagnosed Gallstone Disease or Gallbladder Surgery, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2017–March 2020 and August 2021–August 2023

CHARACTERISTICS | DIAGNOSED DIABETES | | UNDIAGNOSED DIABETES | | PREDIABETES | | NORMAL GLYCEMIA
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 25.2 (22.4–28.1) | 2.6 (2.0–3.3) | 17.9 (13.8–22.9) | 1.7 (1.2–2.4) | 16.6 (14.7–18.7) | 1.4 (1.0–1.9) | 14.8 (11.8–18.4)
Age (years)
20–44 | 12.8 (7.8–20.3) | 1.6 (0.9–3.0) | 19.2 (11.8–29.5) | 2.7 (1.3–5.4) | 7.1 (5.2–9.8) | 1.0 (0.7–1.6) | 5.8 (4.2–8.0)
45–64 | 21.5 (17.5–26.1) | 1.7 (1.1–2.7) | 15.4 (9.5–24.1) | 1.2 (0.6–2.2) | 14.5 (11.7–17.8) | 1.1 (0.7–1.7) | 13.4 (9.8–18.1)
≥65 | 31.2 (28.0–34.7) | 2.0 (1.4–2.8) | 19.6 (13.4–27.7) | 1.1 (0.6–1.9) | 20.6 (18.3–23.3) | 1.2 (0.8–1.7) | 18.2 (13.4–24.2)
Sex
Men | 17.0 (13.8–20.8) | 2.0 (1.1–3.8) | 9.5 (5.8–15.1) | 0.9 (0.4–1.9) | 10.2 (8.4–12.4) | 1.1 (0.6–1.9) | 10.0 (6.2–15.7)
Women | 34.3 (31.0–37.8) | 2.5 (1.9–3.3) | 27.5 (21.2–34.8) | 2.0 (1.3–3.1) | 23.2 (20.1–26.6) | 1.5 (1.0–2.1) | 17.4 (12.7–23.3)
Race/ethnicity
Non-Hispanic White | 28.0 (24.1–32.2) | 2.1 (1.5–2.9) | 20.2 (14.3–27.8) | 1.4 (0.8–2.2) | 17.6 (15.1–20.4) | 1.2 (0.8–1.8) | 15.1 (11.2–20.0)
Non-Hispanic Black | 17.7 (14.3–21.8) | ^3^ | 9.3 (4.8–17.0)^1^ | ^3^ | 10.7 (8.4–13.4) | ^3^ | ^3^
Non-Hispanic Asian | 12.5 (8.4–18.0) | ^3^ | 8.1 (3.5–17.6)^2^ | ^3^ | 9.6 (6.7–13.7) | ^3^ | ^3^
Mexican American | 24.2 (19.4–29.9) | 1.1 (0.6–2.0) | 18.8 (8.8–35.6)^1^ | 0.9 (0.3–2.3) | 18.9 (11.9–28.7) | 0.6 (0.3–1.2) | 21.5 (11.3–36.9)
Other Hispanic | 26.7 (19.7–35.3) | 1.7 (0.9–3.1) | 15.1 (8.2–26.0) | 1.1 (0.4–3.4) | 16.2 (12.6–20.6) | 0.8 (0.5–1.4) | 20.2 (10.8–34.7)
Other | 22.9 (16.3–31.1) | 1.2 (0.5–2.7) | 30.7 (11.9–59.3)^2^ | 2.6 (0.7–9.7) | 21.4 (11.7–36.1) | 1.2 (0.5–3.3) | 24.0 (13.3–39.3)

Diagnosed diabetes is defined as self-reported health care provider diagnosis; undiagnosed diabetes is defined as A1C ≥6.5% or fasting plasma glucose ≥126 mg/dL; prediabetes is defined as A1C 5.7%–6.4% or fasting plasma glucose 100–125 mg/dL; normal glycemia is defined as A1C <5.7% and fasting plasma glucose <100 mg/dL. Diagnosed gallstone disease or gallbladder surgery is defined as self-reported health care provider gallstone disease diagnosis or history of gallbladder surgery. Data are standardized to the National Health Interview Survey 2020 population with diabetes age ≥20 years, using age categories 20–44, 45–64, and ≥65 years. Conversion formulas for A1C and glucose values are available in the Conversions section. A1C, glycated hemoglobin; CI, confidence interval; OR, odds ratio.

* Normal glycemia is the reference group. Odds ratios for the total population are adjusted for age, sex, and race/ethnicity.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Survey 2017–March 2020 and August 2021–August 2023

TABLE 19.

Prevalence and Odds Ratios for Diagnosed Gallstone Disease Among Age-Eligible Medicare Beneficiaries, by Diabetes Status, Age, Sex, Race, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 3.8 (3.8–3.9) | 2.5 (2.4–2.6) | 1.6 (1.5–1.6)
Age (years)
65–69 | 3.2 (3.1–3.3) | 3.3 (3.2–3.4) | 1.0 (1.0–1.0)
70–74 | 3.5 (3.5–3.6) | 2.6 (2.5–2.7) | 1.4 (1.3–1.4)
75–79 | 4.0 (3.9–4.1) | 2.4 (2.3–2.5) | 1.7 (1.6–1.7)
80–84 | 4.3 (4.1–4.4) | 2.1 (2.0–2.2) | 2.1 (2.1–2.2)
≥85 | 4.5 (4.4–4.7) | 2.0 (1.9–2.1) | 2.4 (2.3–2.4)
Sex
Men | 4.1 (4.1–4.2) | 2.6 (2.5–2.7) | 1.6 (1.6–1.7)
Women | 3.4 (3.3–3.4) | 2.3 (2.3–2.4) | 1.5 (1.4–1.5)
Race
White | 3.8 (3.7–3.8) | 2.8 (2.7–2.8) | 1.6 (1.6–1.6)
Black | 3.2 (3.0–3.3) | 3.2 (3.2–3.3) | 1.2 (1.1–1.2)
Other | 4.0 (3.8–4.1) | 2.4 (2.3–2.4) | 1.3 (1.2–1.3)
Region
Northeast | 3.9 (3.8–4.0) | 2.2 (2.2–2.3) | 1.6 (1.6–1.6)
Midwest | 3.4 (3.3–3.5) | 2.5 (2.4–2.6) | 1.5 (1.5–1.6)
South | 3.7 (3.6–3.8) | 2.4 (2.4–2.5) | 1.6 (1.5–1.6)
West | 4.0 (3.9–4.1) | 2.9 (2.9–3.0) | 1.4 (1.4–1.4)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Diagnosed gallstone disease is defined by an ICD-10-CM code K80 in any position on a claim. Beneficiaries were age ≥65 years with any Parts A or B enrollment or Health Maintenance Organization enrollment during the year. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race, and region.

SOURCE: Centers for Medicare and Medicaid Services 5% Denominator and Claims Files, 2022

TABLE 20.

Age-Standardized Prevalence and Odds Ratios for Diagnosed Gallstone Disease Among Medicaid Beneficiaries, by Diabetes Status, Age, Sex, Race/Ethnicity, and Region, U.S., 2022

CHARACTERISTICS | DIABETES | | NO DIABETES
CHARACTERISTICS | Percent (95% CI) | OR* (95% CI) | Percent (95% CI)
Total | 2.4 (2.4–2.4) | 2.4 (2.3–2.4) | 1.0 (1.0–1.0)
Age (years)
19–34 | 2.2 (2.2–2.3) | 3.0 (2.9–3.0) | 0.8 (0.8–0.8)
35–44 | 2.2 (2.1–2.2) | 2.6 (2.6–2.7) | 0.8 (0.8–0.8)
45–54 | 2.2 (2.2–2.2) | 2.3 (2.3–2.4) | 1.0 (1.0–1.0)
55–64 | 2.3 (2.3–2.3) | 2.3 (2.3–2.3) | 1.0 (1.0–1.0)
Sex
Men | 2.4 (2.4–2.4) | 2.2 (2.2–2.2) | 1.1 (1.1–1.1)
Women | 2.0 (2.0–2.0) | 2.8 (2.8–2.9) | 0.7 (0.7–0.7)
Race/ethnicity
Non-Hispanic White | 2.3 (2.3–2.3) | 2.2 (2.2–2.3) | 1.0 (1.0–1.0)
Non-Hispanic Black | 1.9 (1.8–1.9) | 2.3 (2.3–2.3) | 0.7 (0.7–0.7)
Non-Hispanic Asian | 1.9 (1.8–1.9) | 2.7 (2.6–2.7) | 0.8 (0.8–0.8)
Non-Hispanic American Indian/Alaska Native | 2.7 (2.5–2.8) | 2.3 (2.3–2.4) | 1.2 (1.2–1.2)
Non-Hispanic Hawaiian/Pacific Islander | 2.1 (2.0–2.3) | 2.3 (2.2–2.3) | 0.9 (0.9–1.0)
Hispanic, all races | 2.7 (2.6–2.7) | 2.4 (2.4–2.4) | 1.2 (1.2–1.2)
Multiracial/unknown | 2.1 (2.1–2.1) | 2.5 (2.5–2.5) | 0.8 (0.8–0.9)
Region
Northeast | 2.1 (2.1–2.1) | 2.2 (2.2–2.3) | 1.0 (1.0–1.0)
Midwest | 2.0 (2.0–2.1) | 2.2 (2.2–2.2) | 0.9 (0.9–0.9)
South | 2.2 (2.2–2.2) | 2.7 (2.7–2.7) | 0.8 (0.8–0.8)
West | 2.6 (2.5–2.6) | 2.5 (2.5–2.6) | 1.0 (1.0–1.0)

Diabetes is defined by ICD-10-CM codes E10–E11 in any position on a claim. Diagnosed gallstone disease is defined by an ICD-10-CM code K80 in any position on a claim. Beneficiaries were age 19–64 years with any enrollment during the year. Data are standardized to the Medicaid 2019 population with diabetes age 19–64 years, using age categories 19–34, 35–44, 45–54, and 55–64 years. CI, confidence interval; ICD-10-CM, International Classification of Diseases, Tenth Revision, Clinical Modification; OR, odds ratio.

* No diabetes is the reference group. The odds ratio for the total population is adjusted for age, sex, race/ethnicity, and region.

SOURCE: Centers for Medicare and Medicaid Services Denominator and Claims Files, 2022

TABLE 21.

Prevalence / Incidence and Relative Risk of Ultrasound-Diagnosed Gallstone Disease, by Insulin Resistance Status

POPULATION, YEARS (REF.) | SAMPLE SIZE | INSULIN RESISTANCE STATUS | GALLSTONE DISEASE (%) | ADJUSTED OR (95% CI)
U.S. Studies of Gallstone Disease Prevalence
Participants without diagnosed diabetes, NHANES III, 1988–1994 (77) | Men, n=2,672 | [underlined: Fasting serum insulin (pmol/L)]: ≥80 58–<80 46–<58 35–<46 <35 | . 13.4 7.7 5.6 7.1 5.0 | . 0.91 (0.46–1.77) 0.67 (0.32–1.41) 0.67 (0.38–1.16) 0.93 (0.56–1.54) 1.0
Participants without diagnosed diabetes, NHANES III, 1988–1994 (77) | Women, n=2,981 | [underlined: Fasting serum insulin (pmol/L)]: ≥77 56–<77 44–<56 34–<44 <34 | . 27.4 19.5 14.7 11.1 7.6 | . 1.63 (1.11–2.40) 1.50 (1.07–2.10) 1.30 (0.89–1.88) 1.09 (0.74–1.62) 1.0
Recent Non-U.S. Studies of Gallstone Disease Prevalence
Korean women age 30–79 yrs without diabetes, 2006–2007 (101) | 4,125 | All | 4.2
Korean women age 30–79 yrs without diabetes, 2006–2007 (101) | | [underlined: Premenopausal (HOMA-IR)]: 4th quartile 1st quartile | 3.2 | . 0.81 (0.56–1.19) 1.0
Korean women age 30–79 yrs without diabetes, 2006–2007 (101) | | [underlined: Postmenopausal (HOMA-IR)]: 4th quartile 1st quartile WC <85 cm (HOMA-IR): 4th quartile 1st quartile WC ≥85 cm (HOMA-IR): 4th quartile 1st quartile | 5.8 . . 5.2 . . 7.2 | . 1.37 (1.02–1.84) 1.0 . 1.16 (0.74–1.83) 1.0 . 1.54 (1.01–2.36) 1.0
Danish adults age 30–60 yrs, 1993–1994 (87) | 2,650 | Fasting insulin (per 1 mU/L) HOMA-IR [underlined: Metabolic syndrome]: Present Absent | 15.9 | 1.03 (1.01–1.05) 1.18 (1.02–1.36) . 1.51 (1.16–1.96) 1.0
Study of Gallstone Disease Incidence
Italian adults age 30–69 yrs without diabetes, 1985–1993 (102) | 101 cases, 303 controls | Highest insulin quintile | | 2.64 (1.04–6.72)

A conversion formula for insulin values is available in the Conversions section. CI, confidence interval; HOMA-IR, Homeostasis Model Assessment of Insulin Resistance; OR, odds ratio; WC, waist circumference.

SOURCE: References are listed within the table.