# Genetics of Type 2 Diabetes

## Summary

Since early 2007, the establishment of international consortia and biobanks has catalyzed the performance of large-scale genomic studies. These efforts have driven an explosion in the discovery of genetic variation associated with type 2 diabetes. Most studies have involved genetic data captured using genotyping arrays populated by common single nucleotide polymorphisms (SNPs), although a rapid drop in the cost of next-generation sequencing has facilitated a growing number of exome and genome sequencing studies, which can capture increasingly rare variation. Hundreds of independent SNPs have been associated with type 2 diabetes and glycemic traits using genome-wide association studies (GWAS), and their numbers continue to increase. Findings have pointed to both known and novel molecular pathways and increased the understanding of fundamental disease biology.

On the other hand, causal variants have been identified for only a small fraction of the loci identified by GWAS, and a substantial proportion of disease heritability remains unexplained. While combining genetic variation into polygenic scores improves prediction of type 2 diabetes risk substantially beyond that of single variants, such scores are not yet used in clinical practice due to inadequate predictive ability and implementation challenges. Despite including millions of individuals, genetic studies remain limited by the diversity of populations represented, are underpowered to fully capture rare variation of modest effect sizes, and have incomplete ascertainment of alternate (non-SNP) forms of genetic variation.

As the community continues to expand genetic discovery and pursues systematic fine-mapping, platforms that focus on functional variation, systems biology approaches, and expansion to non-European populations, the coming years will witness exponential growth in our understanding of the genetic architecture of metabolic phenotypes related to type 2 diabetes. Whether these findings prove useful in disease prediction or therapeutic decision-making must be tested in rigorously designed clinical trials.

## Introduction

The explosive parallel growth in the prevalences of the related metabolic disorders of obesity and type 2 diabetes in much of the developed and developing world over the past few decades is almost certainly driven by environmental and behavioral factors, as genetic components do not change in an appreciable manner over such a short time. However, several lines of evidence suggest that variation in DNA sequence does contribute to type 2 diabetes risk. First, twin studies have shown that concordance for type 2 diabetes is greater for monozygotic twins (who share 100% of their DNA sequence) than for dizygotic twins (who, like siblings, share approximately 50% of their DNA sequence) (1,2,3,4,5). Second, the incidence of diabetes is much higher in certain racial/ethnic groups, despite environments that are relatively comparable to those of neighboring populations (6,7,8). Third, family history is an independent risk factor for the development of diabetes in population studies (9,10). And fourth, rare familial forms of diabetes, caused by mutations in single genes (hence, termed monogenic or Mendelian), prove that single base pair changes in the coding regions of key genes, which lead to alterations in protein sequence and function, are sufficient to cause hyperglycemia in the diabetic range (Figure 1) (11,12). Consistent with this notion, the estimated heritability of type 2 diabetes ranges from 25%–69% in a set of Scandinavian families (13) to 52% (95% confidence interval [CI] 26%–80%) in the Washington State Twin Registry (14) and as high as 72% in a large international meta-analysis of twin studies (15).

Taken together, these observations illustrate that rapid changes in the global epidemiology of type 2 diabetes are likely caused by environmental and behavioral factors overlaid on a background of genetic predisposition. This genetic predisposition may vary across populations, in some measure due to divergent genetic histories and unequal selection pressures in specific geographic regions; however, this is a topic of continued investigation (16).

Why is genetic exploration relevant? Regardless of whether genetic predictors become useful markers of disease onset or of subtypes in clinical practice, the identification of genetic variants associated with type 2 diabetes illustrates pathogenic mechanisms that may be targeted by future therapies. Because germline genetic variation always predates the onset of disease, the arrow of time establishes a causal relationship that is not evident with other biological associations. Thus, the genetic approach has a unique opportunity to shed light on the pathophysiology of diabetes in its various manifestations, helping to unravel its clinical heterogeneity and potentially refine therapeutic strategies. This article updates the information included in the Diabetes in America, 3rd edition chapter Genetics of Type 2 Diabetes (17).

## Discovery of Genetic Risk Factors for Type 2 Diabetes

Before a draft sequence of the human genome was available, genetic mapping depended on the generation and anchoring of anonymous genetic markers to specific locations in the genome. This task was first achieved by identifying variation in DNA fragments with known cleavage sites (restriction fragment length polymorphisms). Subsequently other markers, such as DNA segments with characteristic repeats (microsatellites) or unique stretches of DNA (sequence tag sites), enabled the introduction of more sophisticated methods (whole-genome linkage analysis and positional cloning) for determining the position of disease-causing genetic variation within the genome. Linkage analysis depends on the co-segregation of a causal mutation and nearby anonymous markers with affected, but not unaffected, members across successive generations in pedigrees. This approach has been successful for gene discovery in diseases that are highly penetrant: where disease-causing alleles are almost always found in individuals with disease and are almost always absent in individuals without disease. For diabetes, linkage analysis facilitated the discovery of the genes that underlie various types of monogenic diabetes, such as maturity-onset diabetes of the young (MODY) (12,18) or neonatal diabetes (19,20,21) (Figure 1); these associations are described in detail in Diabetes in America: Monogenic Forms of Diabetes (22).

However, diabetes is a complex disease, for which liability to disease is determined by hundreds to thousands of genetic variants that are only slightly penetrant and may carry interactions with the environment. Thus, the use of linkage analysis to characterize the genetic basis of common, complex forms of diabetes was far less successful. For type 2 diabetes, no single genetic locus of substantial effect analogous to type 1 diabetes loci exerts a very strong effect in the general population or even in individual family pedigrees. Thus, the effect of genetic variation is probabilistic rather than deterministic; a substantial proportion of people with some risk variants may be disease-free, whereas others who carry protective alleles may instead have type 2 diabetes due to a constellation of other factors.

To demonstrate the effect of genetic variation on human phenotypes, an alternative approach was needed. Association testing quantifies whether a specific allele is significantly overrepresented in diabetes cases compared to controls without diabetes. With large sample size, this method has greater statistical power to detect a common variant of weak effect. The major limitation of this approach was that—prior to 2005—only a handful of variants could be tested at a time, which required prior knowledge of the existence of genetic variants and prior biological knowledge of a role of a given candidate gene in diabetes pathophysiology. Although multiple genetic associations were described before 2005, only two of these have stood the test of time. Both variants change the amino acid sequence in genes that encode antihyperglycemic drug targets: the p.Pro12Ala polymorphism in the peroxisome proliferator-activated receptor gamma 2 (encoded by PPARG) (23) and the p.Glu23Lys polymorphism in the islet ATP-dependent potassium channel Kir6.2 (encoded by KCNJ11) (23,24). A third locus, a noncoding variant in the transcription factor 7-like 2 gene (TCF7L2), was discovered by large-scale association testing in areas of suggestive linkage (25). The TCF7L2 common intronic rs7903146 polymorphism had the strongest statistical association (though with a modest odds ratio ~1.4) seen consistently across multiple studies (Figure 2) (26,27).

The panorama changed dramatically with the advent of genome-wide association studies (GWAS) (28). Several factors coalesced to enable GWAS: the discovery of millions of single nucleotide polymorphisms (SNPs) and their deposition in public databases; the manufacturing of genotyping arrays that could simultaneously query hundreds of thousands of SNPs with great precision and lower cost; the understanding of an underlying correlation structure between SNPs, driven by the finite number of recombination events in human history, which reduced the complexity of the variation to be interrogated; the recognition that the scientific imperative of reproducibility required the acceptance of strict statistical thresholds that accounted for the universe of possible hypotheses in the human genome; and the corollary of such awareness, that for these very small p-values to be achieved, very large sample sizes had to be assembled through international collaboration. Thus, for the first time, most common variants in the human genome (i.e., those with a minor allele frequency >5%) could be tested en masse (Figure 1).

Several independent GWAS (29,30,31,32,33) initially focused predominantly on European ancestry populations and, coupled with the growing scientific exchange that led to successive meta-analyses of ever-increasing size (34,35,36,37,38,39,40), produced a plethora of robust associations. This research changed the landscape of type 2 diabetes-associated variants, which grew from three prior to the GWAS era to several dozen leading up to 2018 and to more than 500 by 2022 (Figure 2). This list has been complemented by the implementation of similar approaches in the discovery of genetic determinants of quantitative glycemic traits (41,42,43,44,45,46,47,48,49,50,51) and other metabolic phenotypes, which share many signals with type 2 diabetes (Figure 3). Additionally, GWAS in non-European ancestry populations (52,53,54,55,56,57,58,59,60,61,62,63,64,65,66,67,68,69,70,71,72,73) and multi-ancestry meta-analyses of many of these studies (64,74,75,76,77,78,79) have identified hundreds of additional type 2 diabetes loci and demonstrated a large overlap in signals across populations. While a 2023 study suggested strong correlation in effect sizes among ancestries for type 2 diabetes (80), the largest GWAS for type 2 diabetes suggest some ancestry-correlated heterogeneity that may be explained by body mass index (BMI), which does vary across ancestries (81).

A particularly illustrative example of a combination of these approaches has been furnished by Moltke et al. (82). On studying the population isolate of Greenland, the study team selected a custom-made SNP array, the Metabochip (83), and focused on quantitative glycemic traits. The team followed up an original signal in TBC1D4 by sequencing the coding regions of this gene and identified a nonsense p.Arg684Ter variant of Inuit ancestry that is common in the Greenlandic population (frequency 17%) and associated with 2-hour glucose and insulin levels. Stop codon homozygotes harbor a tenfold increased risk of type 2 diabetes compared to wild-type allele carriers. Definitive identification of the implicated protein allowed for functional studies: the stop codon induces lower levels of the TBC1D4 protein in human skeletal muscle, causing reduced numbers of the glucose transporter GLUT4 and decreased insulin-stimulated glucose uptake, which lead, in turn, to postprandial hyperglycemia and impaired glucose tolerance.

The first generations of GWAS mainly tested genetic variation that is common across human populations (i.e., minor allele frequencies >5%). At first, only variants directly genotyped by the SNP arrays could be analyzed; subsequently, computational tools were developed to allow for statistical imputation that enabled accurate prediction of ungenotyped variants based on reference genome sequences (e.g., The 1000 Genomes Project Consortium (84)), which more readily allowed meta-analyses of variants tested in GWAS. As reference human genome sequence panels increased in sample size and diversity over time, three major developments occurred: first, high-accuracy imputation became possible for less common variants (i.e., allele frequencies <5%) (85,86); second, targeted genotyping arrays were designed that included less common but likely functional variation (e.g., coding variants) (87); and third, multi-ancestry GWAS analyses improved, with better capture of variants across ancestral groups (88). The combination of these techniques deployed from around 2017, coupled with the development of large population- and hospital-based biobanks, resulted in a dramatic increase in the number of discovered type 2 diabetes loci (Figure 2).

In addition to SNP arrays (which contain both protein-coding and noncoding variation), protein-coding arrays containing selected coding regions were developed with the hope of achieving a more direct link between associated signals and biological function. For example, using data from a genotyping array designed to focus on coding variation (i.e., the ExomeChip), Mahajan et al. identified 40 mostly common coding variant associations, including novel associations at POC5, PNPLA3, LPL, and ANKH (89). Interestingly, “fine-scale mapping” analyses (described further in the Determining the Function of Type 2 Diabetes Genes section) in this study indicated that often the associated coding variant was not the causal variant underlying the type 2 diabetes association signal. This finding suggested that a significant association between a protein-coding variant and disease was not enough to definitively implicate a gene in diabetes pathogenesis and may have identified the wrong gene altogether.

With the advent of new sequencing technologies, the cost of sequencing became dramatically reduced, enabling large-scale sequencing studies and discovery both within the protein-coding portion of the genome (the exome) (e.g., HNF1A p.Glu508Lys) (90,91,92,93), as well as from the full genome (94).

Gene burden analysis is an approach to implicate disease-causing genes by testing groups of variants within a gene together for their association with disease rather than testing single variants. This approach has become more feasible, including in type 2 diabetes, with the increase in the availability of sequencing data in large populations (Figure 4). Typically, the sets of variants within a gene aggregated for gene burden testing are those that are too rare to be tested individually (i.e., allele frequencies of ≤0.1%) and predicted to be functionally consequential (e.g., causing loss of gene function). For example, in a targeted gene burden analysis of SLC30A8, loss-of-function mutations were collectively associated with 65% reduction in risk of type 2 diabetes (95). Gene burden testing of all genes across the genome has also become increasingly possible with growing sequencing studies and development of high-throughput statistical tools. For example, Fuchsberger et al. performed a rare variant burden study in 12,940 individuals, although the study did not identify statistically compelling positive associations, which was likely due to a lack of statistical power (93). Subsequently, Flannick et al. performed gene burden testing using exome data from 20,791 type 2 diabetes cases and 24,440 controls and identified four genes (SLC30A8, MC4R, PAM, and UBE2NL) that were significantly associated with type 2 diabetes risk (91). More recently, large-scale exome sequencing in up to ~450,000 British subjects enrolled in the UK Biobank led to multiple additional gene-level associations with type 2 diabetes and glycemic traits, including some for genes known to cause monogenic diabetes (GCK, HNF1A, HNF4A, and PDX1), as well as novel diabetes genes (GIGYF1, MAP3K15, and FAM234A) (96,97,98,99).

Despite rapidly growing study sizes, exome and genome sequencing studies remain limited by the power to detect single, low frequency variant and gene burden associations. An additional challenge is inference of rare-variant burden contributed by noncoding variants, which is especially difficult owing to the lack of meaningful and well-powered approaches to aggregation, which is a subject of active investigation (100,101). As sequencing becomes more routine across large biobanks, data from millions of subjects will likely help to identify a plethora of such associations for type 2 diabetes.

## Determining the Function of Type 2 Diabetes Genes

Once a region of the genome has been statistically associated with type 2 diabetes beyond reasonable doubt, new questions emerge, all of which are important to understanding genetic mechanisms and the viability of drug development. Such questions include: (i.) What causal variants underlie the signature of association? (ii.) What genes are causally implicated by these variants, and which tissues are etiologically relevant? (iii.) By what genetic and physiological mechanisms does variation in the region influence diabetes risk? (iv.) What direction of perturbation at this locus would be expected to produce a therapeutically beneficial effect on disease development and progression?

To identify where effort should be placed in the overwhelming space of functional experimentation, the research community has engaged in a variety of computational approaches to help prioritize candidate causal variants and genes for further work. For example, in focusing on the first question—identifying causal variants underlying an association signal identified by GWAS—the approach of statistical fine-mapping has been widely utilized (Figure 5) (102). This method can be conceptualized in two parts: first, locus fine-mapping, where the goal is to determine how many independent variants (or signals) contribute to the patterns of association observed in the region; second, signal fine-mapping, where the goal is to construct a “credible set” of variants statistically likely to harbor the true, causal variant for each identified signal. Fine-mapping methods can achieve these goals based on the statistical information alone; however, additional data can be used to further home in on the causal variant with that credible set. First, association data from multiple ancestries can narrow signals owing to different patterns of linkage disequilibrium (LD), meaning genomic variation that tracks together (77). In addition, annotations that label genomic sequences with a function due to their presence in either protein-coding sequence or noncoding sequence with presumed regulatory function (e.g., a promoter or enhancer) can be used to prioritize variants that are most likely to be driving the association signal (Figure 5) (38,77,103,104,105). These approaches are now routinely used in tandem. For example, in a 2022 multi-ancestry meta-analysis, the authors used both differences in LD across populations and functional annotation from diabetes-relevant tissues (e.g., DNA accessibility or chromatin state in islets, adipocytes, or hepatocytes) to determine the fewest number of variants that explained the genetic association at each signal (77).

The second question—which genes are causally implicated by these variants—is challenging but must be addressed to enable appropriate mechanistic studies. It is worth remembering here that although a handful of signals identified for type 2 diabetes include coding variants in the credible set and thus provide a potential candidate gene, the majority of signals map exclusively noncoding variation without an obvious link to a candidate gene (89). As a result, different approaches have been utilized to link variants to genes to generate priorities for further study at the wet-lab bench. These approaches often combine empirical data derived from disease-relevant cell types (e.g., islets, adipocytes, hepatocytes, myocytes), including assessments of how the DNA is folded and which promoters interact with which enhancers (e.g., promoter capture Hi-C) or in silico methods that use known features, such as chromatin state, to predict which genes have altered expression due to a particular variant (Figure 5) (106,107,108). Combining such data in a probabilistic framework can provide estimates that a given gene is causal for type 2 diabetes (109,110). Initial functional studies focused on bulk tissue (i.e., human islets), but the advent of single-cell sequencing approaches allowed a shift to this higher-resolution approach (111,112). Most genes contain variants in their promoters that alter their expression, so it is very important to establish that signals for altered gene expression co-localize with those for diabetes risk (113,114). Advances in understanding the regulatory grammar of DNA have enabled machine learning approaches to predict variants that are most likely to alter gene expression in a given tissue (115,116). Understanding whether changes in gene expression result in a diabetes-relevant cellular phenotype is an important next step and is increasingly being assessed at scale through targeted and genome-wide cellular screening efforts (117,118).

Next, four examples of moving from “variant to function” are summarized, highlighting the challenges of this work, as well as the insights into disease biology that can be provided.

Coding variants provide a molecular “signpost” to the gene underlying the genetic association and have accelerated efforts to translate genetic discoveries into molecular mechanisms. The following examples showcase various approaches that can be taken to understand how genetic factors influence diabetes pathogenesis. For example, in 2007, a common coding variant (p.Arg375Trp) in SLC30A8 was identified in an early type 2 diabetes GWAS (29). SLC30A8 encodes a zinc transporter (ZnT8) that is located in pancreatic islet cells and is integral for zinc ion transport to stabilize insulin and trigger crystallization (119). Whether this diabetes-associated allele resulted in a loss or gain of function was not obvious. For years, there was uncertainty and debate as to how genetic variation in SLC30A8 influenced diabetes risk, since a common risk-associated allele from GWAS cannot inform on whether disease mechanism involves loss or gain of gene function, and mouse models did not have a consistent phenotype (120,121). Compelling evidence for the disease mechanism arrived in 2014 from a human gene burden analysis (Figure 4), described in the previous section, which showed that carriers of protein-truncating variants in SLC30A8 had a 65% reduced risk of type 2 diabetes compared to non-carriers, indicating that loss of function of the gene is protective for diabetes (95). In concordance, newer mouse models carrying the protective p.Trp138* allele had increased capacity to secrete insulin in high-glucose conditions, with secretion of 50% more insulin in response to hyperglycemia (122). Additional studies in humans supported these findings, demonstrating that particular loss-of-function missense mutations in SLC30A8 enhance proinsulin processing and insulin responsiveness to glucose, conferring protection against type 2 diabetes (123).

The SLC16A11 locus provides an illustrative second example both of discovery, this time in a non-European ancestry population, and of insight gained into disease biology from functional studies. A GWAS of populations in Mexico and East Asia first identified 17p13 as a type 2 diabetes genetic risk locus (67,69). The risk haplotype at this region is more common among individuals of Mexican or Latin American ancestry (minor allele frequencies ~30% compared to <2% in European populations) with each allele increasing diabetes risk by approximately 25% (67). Genetic fine-mapping at this locus revealed that some variants decreased SLC16A11 expression in liver, and other variants disrupted the interaction of the SLC16A11 protein (a monocarboxylate transporter) with basigin, a chaperone protein important for plasma membrane localization, leading to reduced cell-surface localization of the SLC16A11 protein (124). Homozygous carriers had up to 85% less SLC16A11 at the plasma membrane. SLC16 family members mediate transport of distinct substrates. Reduced SLC16A11 transport activity at the cell membrane results in alterations in fatty acid and lipid metabolism, driving cellular changes consistent with those seen with insulin resistance. As these findings implicated reduced SLC16A11 activity in risk for developing type 2 diabetes, increasing SLC16A11 function may offer a therapeutic target strategy.

The next example highlights the PAM locus, which was first identified in a glycemic trait exome-array study as harboring coding variants that alter beta cell function, as captured by the insulinogenic index (125). Initially, genetic data alone were insufficient to distinguish whether the association was due to the PAM missense allele or a second missense allele in near perfect LD in the neighboring PPIP5K2 gene. However, a second study in an Icelandic population identified a second missense variant in the PAM gene that was independently associated with altered type 2 diabetes risk, suggesting that PAM was more likely to be the effector gene at this locus (92). Subsequently, gene burden testing of missense variants predicted to be deleterious in PAM provided further support for the gene’s association with diabetes (91,98). Peptidylglycine alpha-amidating monooxygenase (PAM) is an enzyme in neuroendocrine cells that creates peptide amides, increasing peptide biological potency (126,127). PAM is widely expressed, including in both pancreatic beta and alpha cells, where it is involved in regulating insulin secretion (128). Type 2 diabetes-associated PAM alleles result in defective expression and reduced catalytic function, directly reducing pancreatic beta cell insulin content and impairing release in response to glucose (128).

A final example represents the more common signal that researchers need to dissect, as it is a regulatory variant. In an early study that combined fine-mapping with integration of genomic annotation from diabetes-relevant cell types, researchers established that the credible set of variants at the MTNR1B locus contained a signal variant. When they integrated the fine-mapping results with epigenomic data from diabetes-relevant cell types (e.g., pancreatic islets, hepatocytes), they showed that the variant was located in an enhancer and created a binding site for the transcription factor NEUROD1. Using in vitro cellular models, allelic-specific differences were found in NEUROD1 binding to the diabetes risk variant, and in human islets, the type 2 diabetes-associated allele was associated with increased MTNR1B expression (104). MTNR1B encodes the melatonin receptor, which is expressed in human beta cells and plays a role in inhibiting insulin secretion. The diabetes risk allele increases expression of the receptor and is predicted to reduce insulin secretion inappropriately.

## Polygenic Scores for Prediction of Type 2 Diabetes

As a polygenic condition, type 2 diabetes is well appreciated to be genetically determined by thousands of variants. Most genetic discovery, as noted, has involved common variants identified via GWAS, which exert only modest penetrance (i.e., odds ratios typically <1.2) (Figure 2). In isolation, such risk variants have little effect on disease risk; however, combining risk variants together into polygenic scores can improve risk prediction.

Polygenic scores estimating disease risk have been considered in two categories: (i.) “restricted-to-significant” polygenic scores (rsPS), which include only genetic variants significantly associated with disease, and (ii.) “global extended” polygenic scores (gePS), which typically include hundreds of thousands of variants, taking into account redundancy of signals related to correlation (i.e., LD) of variants (129). The ability of a polygenic score to predict future or prevalent disease risk has commonly been quantified using the area under the receiver operator characteristic curve (AUROC) or C statistic. The AUROC measures the predictive efficacy of a test, with a value of 0.5 indicating no greater predictive ability than chance and a value of 1.0 indicating a perfectly predictive test.

The first polygenic scores for type 2 diabetes were rsPS and included between three to a few dozen genetic variants identified in early genetic studies (including pre-GWAS candidate gene studies). While such scores had better predictive ability for future diabetes onset than any single variant, they offered AUROCs on the order of 0.60, which were insufficient for clinical use and inferior to prediction models involving clinical data alone (130,131,132,133). One of the largest rsPS for type 2 diabetes, including 62 SNPs, was tested in the Framingham Offspring Study (FOS) and produced an AUROC of 0.726 for incident diabetes prediction when combined with age and sex, which represented a significant (p<0.001), but minimal, improvement from the model with age and sex alone (AUROC 0.698) (133). Studies have demonstrated that polygenic risk for type 2 diabetes can be offset by environmental factors. For example, the Diabetes Prevention Program showed that an intensive lifestyle intervention, consisting of dietary and physical activity components, is effective even in the quartile of participants with highest type 2 diabetes rsPS (134).

More recently, methods to develop gePS have allowed capture of substantially more variants than in rsPS, including hundreds of thousands of variants with sub-genome-wide significant associations with disease (129). Multiple derivations of gePS for type 2 diabetes have demonstrated some improvement in risk prediction beyond rsPS. Still, even the most recently developed gePS have not generated prediction levels suitable for clinical use, with maximum AUROC estimates of approximately 0.73 in models that include age and sex (Figure 6) (38,135,136). Like the rsPS, the gePS have contributed only incremental improvement when added to models with clinical variables. For example, a model with age, sex, and BMI demonstrated an AUROC of 0.818 for prediction of prevalent diabetes status in the FinnGen Biobank compared to an AUROC of 0.835 when the model also included the gePS (77).

The predictive ability of polygenic scores is poised to improve with forthcoming methods that can incorporate rarer genetic variation. For example, a combined rare and common variant polygenic score was developed for glycated hemoglobin (A1c) (137). This combined polygenic score for A1c identified 4.9 million misdiagnosed type 2 diabetes cases in the United States due to inaccuracies in A1c representation of glycemia given erythrocyte variation—nearly 1.5-fold more people than a common variant polygenic score alone.

Another related application of polygenic scores is identification of individuals with particularly high disease risk. Different score thresholds can be chosen to pinpoint individuals at the greatest genetic risk of diabetes. For example, multiple studies have demonstrated that those in the top 10% of the type 2 diabetes gePS have approximately fivefold increased risk of type 2 diabetes compared to the bottom 10% and around 2.75-fold increased risk compared to the remaining 90% of the population (76,77). For individuals with such high polygenic type 2 diabetes risk, this genetic information could have clinical utility, and studies are ongoing to formally assess this possibility. At the same time, placing such risk estimates in the context of genetic testing for monogenic diabetes, which is performed as part of standard clinical practice, can be helpful. Rare genetic variants causing monogenic diabetes have been estimated in the UK Biobank to confer more than eightfold increased diabetes risk (138,139). Furthermore, in the UK Biobank, people with the highest 1% of the type 2 diabetes gePS were at significantly lower risk of diabetes, with ~20% disease prevalence compared to ~56% prevalence in monogenic diabetes carriers (Figure 6) (138). Further research is necessary to determine whether identifying individuals with high type 2 diabetes polygenic scores, who have essentially moderate disease risk, will be useful clinically. Additionally, even if deemed potentially useful in a particular context (e.g., as part of a clinical risk tool), implementation of polygenic score generation in clinical labs has many challenges, including determining the appropriate risk estimates for individuals of different genetic ancestries.

In addition to predicting future diabetes risk, a potential application of the type 2 diabetes polygenic score is clinical discrimination between type 1 and type 2 diabetes to improve accuracy of subtype designation. A 69-SNP type 2 diabetes rsPS was assessed for this purpose in the Wellcome Trust Case Control Consortium and was unable to provide strong discrimination between type 1 and type 2 diabetes cases (AUROC 0.64). This performance was inferior to a 30-variant type 1 diabetes rsPS, which had an AUROC 0.88 and was only minimally improved (AUROC 0.89) by the addition of the type 2 diabetes score to it (140). Thus, as of 2023, the type 2 diabetes polygenic score is unable to effectively aid diabetes subtyping; however, as described in the next section, additional strategies are being investigated to leverage type 2 diabetes genetic discovery for this purpose.

## Genetic Stratification of Type 2 Diabetes

Type 2 diabetes is a heterogenous disease, with patients displaying varying degrees of pancreatic beta cell dysfunction and insulin resistance (141). In theory, genetics could identify underlying disease pathways leading to type 2 diabetes and allow stratification of patients based on their inherited risk for such pathways contributing to their disease process. The research field has a great interest in grouping type 2 diabetes genetic variants into shared mechanistic categories or pathways.

Prior to 2018, genetic clustering utilized approaches that restricted each locus to be a member of only one cluster, so-called “hard clustering” (36,89,142). These efforts identified some potential disease mechanisms, e.g., groups of loci broadly related to beta cell function and insulin resistance. However, loci with well-appreciated mechanisms were often not grouped in expected clusters, and some clusters were difficult to interpret. In 2018, two papers (89,143) suggested that applying “soft clustering,” where a locus could be involved with multiple pathways, could improve interpretability of genetic clusters. These two independent efforts also converged on a shared set of five clusters that could be readily linked to potential disease processes: two clusters related to distinct mechanisms of impaired beta cell function (termed beta cell and proinsulin by Udler et al. (143)) and three clusters related to different mechanisms of insulin response (termed lipodystrophy, obesity, and liver/lipid (143)) (Figure 7). A sixth, less well-defined cluster was identified by Mahajan et al. (89). Supporting a biological basis of the grouping of loci into clusters, the five clusters described in Udler et al. contained loci significantly enriched for active DNA regulatory elements that were specific to distinct tissues (e.g., the beta cell cluster loci were enriched in pancreatic islets).

A person’s aggregate genetic risk of loci in a given cluster is quantified by generating cluster-specific “partitioned” polygenic scores (pPS), which potentially capture risk for developing diabetes due to a particular disease process (143). In an analysis of ~17,000 individuals with type 2 diabetes, Udler et al. found that cluster pPS were significantly associated with distinct clinical features, suggesting that genetics could help disentangle the heterogeneity of type 2 diabetes. For example, an increased beta cell cluster pPS and proinsulin cluster pPS were each significantly associated with decreased C-peptide levels, supporting a shared disease mechanism of insulin deficiency. Additionally, the pPS could identify individuals with high risk specifically for a given genetic cluster. Thirty percent of individuals had a pPS uniquely in the top 10% of a single cluster, and these individuals also had distinct phenotypes compared to other individuals with type 2 diabetes. For example, those with extreme pPS for the lipodystrophy cluster had significantly decreased high-density lipoprotein (HDL), percent body fat, and BMI compared to all others with type 2 diabetes, mirroring the pattern of clinical phenotypes seen in patients with monogenic forms of lipodystrophy. Associations of the cluster pPS with distinct clinical phenotypes have been replicated in other datasets, and the pPS have differential associations with metabolic outcomes, including coronary artery disease, hypertension, and chronic kidney disease (144). For example, two clusters related to potential mechanisms of insulin resistance had opposite associations with coronary artery disease, with the lipodystrophy pPS increasing disease risk versus the liver/lipid cluster pPS decreasing risk. Subsequent expansion of the clustering work to include 323 type 2 diabetes variants and 64 trait associations identified 10 clusters, recapturing the original clusters along with additional clusters related to mechanisms of insulin deficiency and insulin resistance (145).

While genetic clusters have pointed to potential genetic mechanisms of type 2 diabetes, the currently derived pPS have small effect sizes and, as of 2023, are not useful for individual patient stratification in clinical practice. Nevertheless, analysis of cellular phenotypes in subcutaneous adipocytes derived from human biopsies has demonstrated differences in cellular features between individuals with high versus low lipodystrophy cluster pPS (146). Remarkably, cellular changes, such as the size of lipid droplets and intensity of mitochondrial staining, were visible on images, suggesting that while the effects conferred by the pPS on clinical biomarkers, such as serum lipid levels, may be small, there appear to be quite large effects on cellular features further upstream. As discussed in the Additional Insights Gained section, the specific cellular changes also point to convergence of polygenic and monogenic diabetes genetic pathways.

Genetic clustering has advanced simultaneously with clustering of individuals with diabetes based on clinical features (reviewed in Deutsch et al. (147)). Genetic analyses of some phenotypic diabetes clusters, including with use of pPS, have supported potential etiological differences in clusters (148,149). For example, Mansour Aly et al. demonstrated that in phenotypically derived clusters developed in Scandinavian populations (150), the two cluster pPS capturing forms of insulin deficiency (beta cell and proinsulin clusters) were both most strongly associated with their “Severe Insulin Deficient Diabetes” cluster (148).

## Summary of Type 2 Diabetes Genetics

The tremendous success of GWAS and their follow-up for type 2 diabetes and other human phenotypes has resulted in several insights into the genetic architecture of disease:

- More than 500 independent loci have been associated with type 2 diabetes, with the vast majority of findings coming from GWAS.
- Most type 2 diabetes-associated loci are located near genes previously not suspected of playing a role in type 2 diabetes pathophysiology.
- The genes harboring the functional variants at most loci remain unknown.
- A handful of robust gene-level associations have been identified using gene burden analyses in sequencing data.
- The road from association to function is arduous and may involve fine-scale mapping, deployment of various -omics data, and wet-bench lab experiments. All of these techniques are important for characterizing the biological system to establish function. Techniques within the -omics field can probe the effect of genetic variation on RNA, protein, metabolites, and other biologically relevant structures, making these technologies key to this process.
- Type 2 diabetes polygenic scores have not yet demonstrated utility for standard clinical practice.
- Efforts to group type 2 diabetes genetic variants by shared physiology into clusters have enabled the generation of cluster-specific polygenic scores with distinct associations with clinical phenotypes, but such approaches are not yet clinically useful at the individual level.

## Additional Insights Gained

Pleiotropy is the idea that a single genetic variant or gene can have multiple, unrelated biological effects. Pervasive pleiotropy exists for loci associated with type 2 diabetes—with considerable complexity—which can be exploited. One notable observation following the success of association studies is the extent to which specific signals for type 2 diabetes often demonstrate association with a wider spectrum of additional traits, including cardiometabolic risk factors. Pleiotropy—a term used to describe this general phenomenon—turns out to be pervasive across the human genome (151). This phenomenon is nicely exemplified for type 2 diabetes by the glucokinase regulatory protein gene, GCKR. Genetic variation in this gene has been associated with numerous traits, including type 2 diabetes, serum triglyceride levels, and fasting glucose (152), as well as dozens of others. Genomic regions containing type 2 diabetes-associated loci display considerable shared associations with other cardiometabolic traits, including fasting glucose, systolic blood pressure, triglycerides, and BMI (Figure 3). Looking exclusively at the lead variant associated with type 2 diabetes at each of the 520 established signals reported to date, 71% carry nominal association (at a less rigorous p<1x10^-3^) with at least one of these traits; 10% carry association with three or four traits. Rather than focus on associations that are nearby, work in the 2020s has taken this analysis a step further, utilizing computational analyses to map the set of loci where these associations implicate a singular genetic change with multiple predisposing risk factors and increased risk to type 2 diabetes though formal statistical colocalization (153).

Beyond quantifying subtypes within the spectrum of diabetes patients, as discussed in the Genetic Stratification of Type 2 Diabetes section, multi-trait association data may be quite useful to indicate the expected physiological effect broadly if the target in the region were perturbed, i.e., “on target” effects beyond the central type 2 diabetes indication. For example, taking this approach and focusing on coding variation at the glucagon-like peptide-1 (GLP-1) receptor gene, Scott et al. contrasted the effects expected from genetic perturbation with GLP-1 receptor agonists, showing consistency with (lower) fasting glucose, but also evidence of lower risk for type 2 diabetes and coronary heart disease (154). Data and examples like this one can help prioritize targets with ideal physiological drug-targeting properties to maximize success in downstream safety trials, as well as to deprioritize targets that may be predicted to cause negative physiological responses through on-target perturbations.

Type 2 diabetes and monogenic diabetes overlap genetically. While large-scale genomic studies for type 2 diabetes have implicated many genes not previously connected to diabetes, variation near or within monogenic diabetes genes has been consistently associated with risk of type 2 diabetes (90,155,156). For example, in HNF1A, a gene causing a subtype of MODY, the p.Glu508Lys variant, which is present in 0.3% of people of Latino ancestry, was identified in exome sequencing of Mexican people and found to confer approximately fourfold increased risk of type 2 diabetes. In experimental models capturing its impact on gene expression, this variant demonstrated reduced transactivation activity of its target promoter at an intermediate level between the wild-type HNF1A protein and those with mutations causing MODY. Subsequent large-scale sequencing studies, as noted, have demonstrated that individuals with type 2 diabetes carry more rare variants in monogenic diabetes genes than would be expected by chance (91,96,157). Additionally, type 2 diabetes risk variants generating the lipodystrophy cluster pPS (143), as described in the Genetic Stratification of Type 2 Diabetes section, define a cellular phenotype in human subcutaneous adipocytes (involving increased mitochondrial activity and decreased lipid accumulation) that mirrors cellular changes seen in monogenic lipodystrophy (146). Together, these findings suggest that patients with monogenic diabetes and type 2 diabetes exist along a continuum rather than in discrete binary categories. Further supporting the idea of a continuum, population-based studies of people with pathogenic genetic variants expected to cause monogenic diabetes have demonstrated less severe clinical phenotypes than classically described (138,139).

Genetic studies augment prior epidemiological observations. Several of the strongest genetic associations for BMI (e.g., the FTO-IRX3-IRX5 and MC4R loci) are also strongly associated with susceptibility to type 2 diabetes. Furthermore, the alleles that increase BMI also increase susceptibility to type 2 diabetes, which is broadly consistent with prior epidemiological studies. This result is fully expected because BMI is a causal risk factor for type 2 diabetes. One would expect that genetic variants that modify any type 2 diabetes causal risk factor should also modify type 2 diabetes susceptibility. This idea can, thereby, be used to generate novel discovery: that is, the observation that genetic variants associated with an exposure in aggregate also modify type 2 diabetes susceptibility is evidence that this exposure is causal.

Under specific assumptions, potential causal exposure/outcome hypotheses can be statistically evaluated by using genetic variants for the exposures in an instrumental variable analysis framework (158). This framework, dubbed Mendelian randomization, has seen dramatic expansion and utilization in the last decade, given the substantial growth of genetic association data, to search broadly for causal risk factors for disease. In the context of type 2 diabetes, this approach has led to some interesting (perhaps provocative) statistical observations (159). For example, genetically elevated testosterone levels increase susceptibility to type 2 diabetes in women, but decrease type 2 diabetes risk in men (160). In contrast to the well-established protective effects of lower low-density lipoprotein (LDL) on heart disease, reduced LDL cholesterol levels may increase susceptibility to type 2 diabetes (161,162). For example, there is a higher risk of type 2 diabetes in individuals who take statins, which lower cholesterol levels (163), and a lower prevalence of type 2 diabetes is observed in patients with familial hypercholesterolemia (164). Distinguishing between correlation and causality for these observations is certainly a key objective for future work.

## Limitations of Current Approaches (and Their Solutions)

Despite the overwhelming success of large-scale human genetic studies in advancing knowledge of the genetic determinants of type 2 diabetes, a number of limitations must be recognized. These limitations have been identified by the research community and are being addressed to complement gaps in our understanding.

Persistent overrepresentation of individuals of European ancestry in GWAS. The past 15 years have seen a welcome and much-needed increase in the diversity of population groups where GWAS for type 2 diabetes have been performed. These groups include East Asian (56,57,58,59,60,61,62,63,69,71,165), South Asian (53,65,66,78), African American (54,70,76), Latin American and Hispanic (52,55,67,76), and Native American (68,75) populations (Figure 2). As consortia assembling these data perform large-scale, multi-ancestry meta-analyses (75,76,77,165), more novel findings are expected to come to light. Still, even if all existing data were combined, the proportion of samples for the genetics of type 2 diabetes would not reflect the national distribution of these groups across the United States, much less the distribution of these populations across the world. To maximize the power for discovery and the translational benefits of these discoveries for everyone, continued inclusion efforts at scale in GWAS and generally in multi-omics resources are essential. DNA Biobanks—like those of the Million Veteran Program (MVP) or the All of Us cohort, to name a couple—are poised to close some of the gaps, although additional efforts to expand collections and integrate with existing data are a clear direction of growth in years to come.

Polygenic scores derived from European populations do not translate well across other ancestral groups. As polygenic scores have been developed primarily in European populations, prediction has been most accurate in populations of matched ancestry, with poorer performance in other groups. For example, the performance of the 23andMe gePS score published in 2019 declined from an AUROC of 0.652 in a people of European ancestry to 0.588 in those of African American ancestry (136). Trans-ancestry polygenic scores are being developed using modeling to derive variant weights without the need for a priori population assignment (e.g., Ge et al. (166)). However, such scores still suffer from relatively low AUROC values, reflecting the need for further refinement before clinical applications are possible.

Most analyses have not considered interactions with the environment and sex. Type 2 diabetes results from complex interactions among multiple genetic and environmental factors, and the rapid rise of its prevalence cannot be attributed to genetics. Because most GWAS are designed to detect loci that have primary effects on type 2 diabetes risk, regardless of the environmental context, many variants whose impact varies according to an environmental parameter might be missed. This effect is due in part to the imprecision inherent to environmental measures and the noise introduced by a single cross-sectional environmental exposure. In contrast, genotyping methods are extremely accurate, and the genetic exposure is uniform across an individual’s lifetime. Nevertheless, analytical methods are being developed that allow for the joint inquiry of main gene effects and gene × environment interactions (167). These methods have already been deployed to identify loci for insulin sensitivity (43) and the regulation of BMI (168). In the future, genetic biobanks that are richly phenotyped, where environmental factors on diet, geography, or other factors are included, may offer the potential to further advance studies of gene × environment interactions. For example, a 2022 study reported numerous loci associated with a collection of physical activity traits (169), and identifying specific physical activity × type 2 diabetes interactions is a clear direction for future research. Finally, new statistical methods are available that can also identify effects of gene × environment even when the exact risk factor is not known (170). These methods are limited only by statistical power, and thus, the samples sizes provided by biobanks are uniquely powered for this type of discovery effort.

A second variable routinely included in genetic association studies of type 2 diabetes is biological sex. However, sex-stratified analyses have been performed for type 2 diabetes (39,165) and fasting glucose/insulin (49) to identify associations that may differ between sexes. While a scant handful of loci appear to have differences between sexes, this heterogeneity can be of epidemiological interest. For example, in a large-scale study in individuals of East Asian ancestry, Spracklen et al. identified a compelling type 2 diabetes association in males but not in females at the ALDH2 locus (165). ALDH2 is a well-known locus related to alcohol metabolism, suggesting that difference in type 2 diabetes susceptibility attributed at this locus may be explained in part by behavioral differences in alcohol consumption between sexes and the downstream effects on metabolic traits this may impart (165,171).

Progress on understanding the genetics of complications of diabetes. While large-scale genetic studies for type 2 diabetes have been performed, progress on understanding the basis of risk for diabetic complications has met with variable success depending on the trait. Certainly, environmental factors, particularly glycemic control, have a large effect on the risk of developing complications. Yet, these factors do not completely explain the risk for complications, which is further influenced by genetic background. Knowledge of genetic contributions to relatively common traits for which people with diabetes are at elevated risk has advanced significantly, including for coronary artery disease (172), peripheral artery disease (173), stroke (174), and chronic kidney disease (175). However, genetic loci that specifically elevate risk of these complications in type 2 diabetes patients have not been obviously detected despite relatively large sample sizes, for example in coronary artery disease (176). Thus, the excess risk for these conditions that is conferred by type 2 diabetes has not been explained. With complications specific to diabetes—diabetic retinopathy, diabetic kidney disease, or diabetic neuropathy—advances have been limited by the lack of sufficient well-phenotyped samples. Potentially, biobanks that are richly phenotyped may offer a pathway to address this challenge, e.g., predicting diabetic retinopathy using a type 2 diabetes polygenic risk score (76). However, electronic health record data, from which a diabetes complication phenotype could be defined, are quite noisy and require substantial effort to construct high-quality, accurate phenotypes where the proper order of disease progression to complication can be determined. Pooling efforts across multiple biobanks to make progress on understanding excess risk for complications, as well as predicting which type 2 diabetes patients are most liable to develop various comorbidities, offers a very promising direction for future work.

Most analyses are simple additive tests for association and do not explore more complex modes of inheritance. There are good statistical reasons for this approach, a model in which the presence of two copies of the risk allele in an individual essentially doubles the risk associated with a single allele. This assumption may not always be the case: in the two extreme examples, under a dominant model, two copies of the risk allele will not add any further risk to that conferred by a single copy, and under a recessive model, the risk will not be made manifest unless both copies are present. O’Connor et al. conducted a GWAS using a recessive model for type 2 diabetes and identified 51 loci associated with type 2 diabetes, including five variants undetected by prior additive analysis (177). One low-frequency variant, rs115018790, which colocalization analysis linked to reduced expression of PELO, had an odds ratio of 2.56 for type 2 diabetes in homozygous carriers. While most type 2 diabetes-associated SNPs exert their action via an additive model, this is expected as their discovery took place precisely under such a model. A comprehensive examination of alternative modes of inheritance is needed in existing GWAS datasets, which now are reaching adequate sizes to compensate for the smaller number of homozygous minor allele carriers and for the penalty incurred by additional statistical testing. Similarly, tests of gene × gene interactions (epistasis) and accounting for divergent effects depending on parental line of inheritance, where that information is available (178), are likely to yield additional loci.

## The Future of Research on the Genetics of Type 2 Diabetes

Given the rapid progress achieved in genetic discovery in type 2 diabetes and the multipronged approach deployed to overcome experimental limitations, the research community holds great hope that the pace will be maintained and a substantial part of the genetic architecture of type 2 diabetes will be elucidated in the coming years. If this vision is realized, several conceptual advances can be expected:

The nosology of disease will be refined. Type 2 diabetes, diagnosed solely on the basis of the final common pathway of hyperglycemia, is likely a heterogeneous syndrome that can be caused by a variety of processes (179). Genetic etiologies have already helped classify the various forms of monogenic diabetes, and an analogous genetic subclassification of type 2 diabetes informed by physiology is beginning to emerge (e.g., Udler et al. (143)).

Additional disease pathways will be identified. Unsuspected biology has already been uncovered via genetic discovery. For example, human genomic studies followed by elegant functional studies of TM6SF2 and PNPLA3 have implicated liver lipid metabolism in the pathogenesis of both type 2 diabetes and fatty liver disease (180). The increasing number of genetic loci at hand and availability of -omics tools (e.g., transcriptomics, epigenomics, metabolomics) will facilitate discovery and refined understanding of disease pathways, some of which may be amenable to the development of new therapeutics.

Genetic discovery may identify drug targets. Among the initial type 2 diabetes genetic associations were coding variants in PPARG, the gene that encodes the target of thiazolidinediones (23), and KCNJ11/ABCC8, the genes that encode the targets for sulfonylureas (24,181). More recent studies have identified the target for GLP-1 receptor agonists as another type 2 diabetes-associated gene (182,183). Additionally, multiple companies have developed glucokinase activators, which piggyback on years of research of GCK’s role in regulating glucose homeostasis and causing MODY (41,184,185). While debate continues around whether glucokinase activators are a safe and effective treatment for diabetes (186,187,188,189), all of these examples represent proof of principle for the potential for genetic discovery to aid drug development. Aggregating -omics data in humans and model systems, as well as ancillary associations that might point to off-target effects, will be essential for the genomic revolution to catalyze new drug discovery.

Treatment paradigms will be modified. Pharmacotherapy in type 2 diabetes is often selected based on patient comorbidities, medication side effects, cost, and availability, without consideration of the underlying pathophysiology driving disease phenotype (190). Pharmacogenetics is a promising precision medicine approach to tailor treatment choices by a patient’s underlying genetic background (191,192). Specific loci have been implicated in the response to metformin (193,194,195), sulfonylureas (196), and GLP-1 receptor agonists (197,198,199,200). Using genetics to guide medication selection might orchestrate a greater improvement in A1c, decrease risk for comorbidities, or suggest lower medication doses, reducing side effects.

Stratification of patients may allow for better targeting of public health or clinical trial interventions. Some preventive or therapeutic measures may be too expensive to deploy in the population at large, or they may be futile in specific subgroups. Genetic characterization may help identify the groups of people more likely to benefit from particular public health strategies, for example, those at highest genetic, as well as socioeconomic, risk (201). Similarly, the efficiency of clinical trials may be enhanced by enrolling participants who are more likely to reach the desired endpoints or benefit from the agents being tested, as has been demonstrated already for an atherosclerotic disease gePS in a trial for evolocumab (202).

Genetics may facilitate the implementation of precision or personalized medicine. Though it is not yet clear that genetic information will be powerful enough to apply therapeutic decisions at the individual level, it may help do so for specific subgroups. For example, genetic approaches may identify groups of individuals who are more likely to develop a particular diabetes complication. For such an approach to be feasible, researchers envision that in the not-too-distant future any individual who joins a public or private health care system would be genotyped or sequenced for the full list of actionable genetic variants (e.g., those that modify risk of common diseases or response to available medications), such that his/her information is available in the electronic medical record. When the time comes to make specific screening or therapeutic decisions, genetic information filtered through appropriate decision support tools would automatically guide the practitioner into the course of action most appropriate to the person and situation at hand.

Large-scale consortia efforts are critical for advancement of precision medicine. The genetics community has demonstrated the value of large-scale collaborative science for the development and deployment of novel methods and the discovery of robust disease associations. As the field accelerates efforts to move from genetic discovery to molecular mechanism, this ethos needs to be extended to capture new communities and data types. The International Common Disease Alliance (ICDA) seeks to catalyze these efforts by bringing expertise together, thus reducing redundancy and increasing efficiency. For type 2 diabetes, the Accelerated Medicines Partnership for Common Metabolic Disorders (AMP-CMD) provides a focus for the diabetes community, initially bringing genetic and genomic data together, but increasingly extending this to epigenomic and cellular data. The American Diabetes Association (ADA) and the European Association for the Study of Diabetes (EASD) support efforts to provide consensus guidelines on how genetics can be incorporated into precision medicine efforts for diabetes diagnosis, prognosis, and treatment. Moving forward, all efforts must be inclusive and aim to reduce health disparities.

## Conclusion

In summary, the field of type 2 diabetes genetics has experienced a steep discovery curve, and efforts now focus on translation of findings to improve understanding of pathophysiology and augment disease risk prediction. Progress has been uneven, with most efforts focused on common variants and populations of European ancestry. However, concerted efforts are being made to improve the diversity of genetic studies, in part facilitated by the emergence and growth of biobanks. Larger and more diverse study populations with both clinical and genetic phenotyping, along with the improving affordability of sequencing technologies and the continued development of analytical tools, contribute to an optimistic outlook for the future. Whether this newfound knowledge will translate into improved patient care depends on the success of basic science to identify causal risk genes and their mechanisms, the development of polygenic scores with enhanced predictive ability, and the opportunity to design and execute genetically based and outcomes-driven clinical trials.

## List of Abbreviations

A1c: glycated/glycosylated hemoglobin
AUROC: area under the receiver operator characteristic curve
BMI: body mass index
gePS: global extended polygenic score
GLP-1: glucagon-like peptide-1
GWAS: genome-wide association study
LD: linkage disequilibrium
MODY: maturity-onset diabetes of the young
PAM: peptidylglycine alpha-amidating monooxygenase
pPS: partitioned polygenic score
rsPS: restricted-to-significant polygenic score
SNP: single nucleotide polymorphism

## Funding

Dr. Kreienkamp is supported by a training grant from the National Institute of General Medical Sciences (T32GM774844). Dr. Voight is supported by a grant from the National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK; UM1DK126194). Dr. Gloyn is a Wellcome Senior Fellow in Basic Biomedical Science and is funded by Wellcome (200837), the NIDDK (UM1DK126185), and the Stanford Diabetes Research Center (P30DK116074). Dr. Udler is supported by the NIDDK (K23DK114551, R03DK131249), the Clinical Scientist Development Award from the Doris Duke Charitable Foundation, and the Massachusetts General Hospital Transformative Scholars Award.

## Acknowledgments

The authors thank Jason Flannick for code and time provided to help generate Figure 2 and Kirk Smith for his assistance in developing Figure 7.

This is an update of: Florez JC, Udler MS, Hanson RL: Genetics of Type 2 Diabetes. Chapter 14 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 14.1–14.25

## Article History

Received in final form on August 23, 2023.

## References

1 Barnett AH, Eff C, Leslie RD, Pyke DA. Diabetes in identical twins. A study of 200 pairs. Diabetologia. 1981;20(2):87-93. doi:10.1007/BF00262007 7193616
2 Newman B, Selby JV, King MC, Slemenda C, Fabsitz R, Friedman GD. Concordance for type 2 (non-insulin-dependent) diabetes mellitus in male twins. Diabetologia. 1987;30(10):763-768. doi:10.1007/BF00275741 3428496
3 Kaprio J, Tuomilehto J, Koskenvuo M, et al. Concordance for type 1 (insulin-dependent) and type 2 (non-insulin-dependent) diabetes mellitus in a population-based cohort of twins in Finland. Diabetologia. 1992;35(11):1060-1067. doi:10.1007/BF02221682 1473616
4 Meigs JB, Muller DC, Nathan DM, Blake DR, Andres R, Baltimore Longitudinal Study of Aging. The natural history of progression from normal glucose tolerance to type 2 diabetes in the Baltimore Longitudinal Study of Aging. Diabetes. 2003;52(6):1475-1484. doi:10.2337/diabetes.52.6.1475 12765960
5 Poulsen P, Kyvik KO, Vaag A, Beck-Nielsen H. Heritability of type II (non-insulin-dependent) diabetes mellitus and abnormal glucose tolerance—a population-based twin study. Diabetologia. 1999;42(2):139-145. doi:10.1007/s001250051131 10064092
6 Bennett PH, Burch TA, Miller M. Diabetes mellitus in American (Pima) Indians. Lancet. 1971;2(7716):125-128. doi:10.1016/s0140-6736(71)92303-8 4104461
7 Ferrannini E, Nannipieri M, Williams K, Gonzales C, Haffner SM, Stern MP. Mode of onset of type 2 diabetes from normal or impaired glucose tolerance. Diabetes. 2004;53(1):160-165. doi:10.2337/diabetes.53.1.160 14693710
8 Knowler WC, Pettitt DJ, Saad MF, Bennett PH. Diabetes mellitus in the Pima Indians: incidence, risk factors and pathogenesis. Diabetes Metab Rev. 1990;6(1):1-27. doi:10.1002/dmr.5610060101 2192853
9 Lyssenko V, Almgren P, Anevski D, et al. Predictors of and longitudinal changes in insulin sensitivity and secretion preceding onset of type 2 diabetes. Diabetes. 2005;54(1):166-174. doi:10.2337/diabetes.54.1.166 15616025
10 Wilson PW, Meigs JB, Sullivan L, Fox CS, Nathan DM, D’Agostino RB, Sr. Prediction of incident diabetes mellitus in middle-aged adults: the Framingham Offspring Study. Arch Intern Med. 2007;167(10):1068-1074. doi:10.1001/archinte.167.10.1068 17533210
11 Velho G, Froguel P. Genetic, metabolic and clinical characteristics of maturity onset diabetes of the young. Eur J Endocrinol. 1998;138(3):233-239. doi:10.1530/eje.0.1380233 9539292
12 Fajans SS, Bell GI, Polonsky KS. Molecular mechanisms and clinical pathophysiology of maturity-onset diabetes of the young. N Engl J Med. 2001;345(13):971-980. doi:10.1056/NEJMra002168 11575290
13 Almgren P, Lehtovirta M, Isomaa B, et al. Heritability and familiality of type 2 diabetes and related quantitative traits in the Botnia Study. Diabetologia. 2011;54(11):2811-2819. doi:10.1007/s00125-011-2267-5 21826484
14 Avery AR, Duncan GE. Heritability of type 2 diabetes in the Washington State Twin Registry. Twin Res Hum Genet. 2019;22(2):95-98. doi:10.1017/thg.2019.11 31124778
15 Willemsen G, Ward KJ, Bell CG, et al. The concordance and heritability of type 2 diabetes in 34,166 twin pairs from international twin registers: the Discordant Twin (DISCOTWIN) Consortium. Twin Res Hum Genet. 2015;18(6):762-771. doi:10.1017/thg.2015.83 26678054
16 Hanson RL, Van Hout CV, Hsueh WC, et al. Assessment of the potential role of natural selection in type 2 diabetes and related traits across human continental ancestry groups: comparison of phenotypic with genotypic divergence. Diabetologia. 2020;63(12):2616-2627. doi:10.1007/s00125-020-05272-8 32886191
17 Florez JC, Udler MS, Hanson RL. Genetics of Type 2 Diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018:14.1-14.25:chap 14. Accessed December 12, 2023. https://www.ncbi.nlm.nih.gov/books/NBK567998/
18 Vaxillaire M, Froguel P. Genetic basis of maturity-onset diabetes of the young. Endocrinol Metab Clin North Am. 2006;35(2):371-384. doi:10.1016/j.ecl.2006.02.009 16632099
19 Gloyn AL, Pearson ER, Antcliff JF, et al. Activating mutations in the gene encoding the ATP-sensitive potassium-channel subunit Kir6.2 and permanent neonatal diabetes. N Engl J Med. 2004;350(18):1838-1849. doi:10.1056/NEJMoa032922 15115830
20 Babenko AP, Polak M, Cavé H, et al. Activating mutations in the ABCC8 gene in neonatal diabetes mellitus. N Engl J Med. 2006;355(5):456-466. doi:10.1056/NEJMoa055068 16885549
21 Sagen JV, Ræder H, Hathout E, et al. Permanent neonatal diabetes due to mutations in KCNJ11 encoding Kir6.2: patient characteristics and initial response to sulfonylurea therapy. Diabetes. 2004;53(10):2713-2718. doi:10.2337/diabetes.53.10.2713 15448106
22 Salguero MV, Arosemena M, Pollin T, et al. Monogenic Forms of Diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/n/diaonline/monogenic
23 Altshuler D, Hirschhorn JN, Klannemark M, et al. The common PPARgamma Pro12Ala polymorphism is associated with decreased risk of type 2 diabetes. Nat Genet. 2000;26(1):76-80. doi:10.1038/79216 10973253
24 Gloyn AL, Weedon MN, Owen KR, et al. Large-scale association studies of variants in genes encoding the pancreatic β-cell KATP channel subunits Kir6.2 (KCNJ11) and SUR1 (ABCC8) confirm that the KCNJ11 E23K variant is associated with type 2 diabetes. Diabetes. 2003;52(2):568-572. doi:10.2337/diabetes.52.2.568 12540637
25 Grant SF, Thorleifsson G, Reynisdottir I, et al. Variant of transcription factor 7-like 2 (TCF7L2) gene confers risk of type 2 diabetes. Nat Genet. 2006;38(3):320-323. doi:10.1038/ng1732 16415884
26 Cauchi S, El Achhab Y, Choquet H, et al. TCF7L2 is reproducibly associated with type 2 diabetes in various ethnic groups: a global meta-analysis. J Mol Med (Berl). 2007;85(7):777-782. doi:10.1007/s00109-007-0203-4 17476472
27 Udler MS, Florez JC. Diabetes genomics. In: Ginsburg GS, Willard HF, David SP, eds. Genomic and Personalized Medicine: Primary Care. 3rd ed. Academic Press; 2017:245-282.
28 McCarthy MI, Abecasis GR, Cardon LR, et al. Genome-wide association studies for complex traits: consensus, uncertainty and challenges. Nat Rev Genet. 2008;9(5):356-369. doi:10.1038/nrg2344 18398418
29 Sladek R, Rocheleau G, Rung J, et al. A genome-wide association study identifies novel risk loci for type 2 diabetes. Nature. 2007;445(7130):881-885. doi:10.1038/nature05616 17293876
30 Diabetes Genetics Initiative of Broad Institute of Harvard and MIT, Lund University, Novartis Institutes of BioMedical Research, et al. Genome-wide association analysis identifies loci for type 2 diabetes and triglyceride levels. Science. 2007;316(5829):1331-1336. doi:10.1126/science.1142358 17463246
31 Zeggini E, Weedon MN, Lindgren CM, et al. Replication of genome-wide association signals in UK samples reveals risk loci for type 2 diabetes. Science. 2007;316(5829):1336-1341. doi:10.1126/science.1142364 17463249
32 Scott LJ, Mohlke KL, Bonnycastle LL, et al. A genome-wide association study of type 2 diabetes in Finns detects multiple susceptibility variants. Science. 2007;316(5829):1341-1345. doi:10.1126/science.1142382 17463248
33 Steinthorsdottir V, Thorleifsson G, Reynisdottir I, et al. A variant in CDKAL1 influences insulin response and risk of type 2 diabetes. Nat Genet. 2007;39(6):770-775. doi:10.1038/ng2043 17460697
34 Zeggini E, Scott LJ, Saxena R, et al. Meta-analysis of genome-wide association data and large-scale replication identifies additional susceptibility loci for type 2 diabetes. Nat Genet. 2008;40(5):638-645. doi:10.1038/ng.120 18372903
35 Voight BF, Scott LJ, Steinthorsdottir V, et al. Twelve type 2 diabetes susceptibility loci identified through large-scale association analysis. Nat Genet. 2010;42(7):579-589. doi:10.1038/ng.609 20581827
36 Scott RA, Scott LJ, Mägi R, et al. An expanded genome-wide association study of type 2 diabetes in Europeans. Diabetes. 2017;66(11):2888-2902. doi:10.2337/db16-1253 28566273
37 Xue A, Wu Y, Zhu Z, et al. Genome-wide association analyses identify 143 risk variants and putative regulatory mechanisms for type 2 diabetes. Nat Commun. 2018;9(1):2941. doi:10.1038/s41467-018-04951-w 30054458
38 Mahajan A, Taliun D, Thurner M, et al. Fine-mapping type 2 diabetes loci to single-variant resolution using high-density imputation and islet-specific epigenome maps. Nat Genet. 2018;50(11):1505-1513. doi:10.1038/s41588-018-0241-6 30297969
39 Morris AP, Voight BF, Teslovich TM, et al. Large-scale association analysis provides insights into the genetic architecture and pathophysiology of type 2 diabetes. Nat Genet. 2012;44(9):981-990. doi:10.1038/ng.2383 22885922
40 Scott RA, Lagou V, Welch RP, et al. Large-scale association analyses identify new loci influencing glycemic traits and provide insight into the underlying biological pathways. Nat Genet. 2012;44(9):991-1005. doi:10.1038/ng.2385 22885924
41 Dupuis J, Langenberg C, Prokopenko I, et al. New genetic loci implicated in fasting glucose homeostasis and their impact on type 2 diabetes risk. Nat Genet. 2010;42(2):105-116. doi:10.1038/ng.520 20081858
42 Knowles JW, Xie W, Zhang Z, et al. Identification and validation of N-acetyltransferase 2 as an insulin sensitivity gene. J Clin Invest. 2015;125(4):1739-1751. doi:10.1172/JCI74692 25798622
43 Manning AK, Hivert MF, Scott RA, et al. A genome-wide approach accounting for body mass index identifies genetic variants influencing fasting glycemic traits and insulin resistance. Nat Genet. 2012;44(6):659-669. doi:10.1038/ng.2274 22581228
44 Prokopenko I, Poon W, Mägi R, et al. A central role for GRB10 in regulation of islet function in man. PLoS Genet. 2014;10(4):e1004235. doi:10.1371/journal.pgen.1004235 24699409
45 Saxena R, Hivert MF, Langenberg C, et al. Genetic variation in GIPR influences the glucose and insulin responses to an oral glucose challenge. Nat Genet. 2010;42(2):142-148. doi:10.1038/ng.521 20081857
46 Soranzo N, Sanna S, Wheeler E, et al. Common variants at 10 genomic loci influence hemoglobin A(1C) levels via glycemic and nonglycemic pathways. Diabetes. 2010;59(12):3229-3239. doi:10.2337/db10-0502 20858683
47 Strawbridge RJ, Dupuis J, Prokopenko I, et al. Genome-wide association identifies nine common variants associated with fasting proinsulin levels and provides new insights into the pathophysiology of type 2 diabetes. Diabetes. 2011;60(10):2624-2634. doi:10.2337/db11-0415 21873549
48 Chen J, Spracklen CN, Marenne G, et al. The trans-ancestral genomic architecture of glycemic traits. Nat Genet. 2021;53(6):840-860. doi:10.1038/s41588-021-00852-9 34059833
49 Lagou V, Mägi R, Hottenga JJ, et al. Sex-dimorphic genetic effects and novel loci for fasting glucose and insulin variability. Nat Commun. 2021;12(1):24. doi:10.1038/s41467-020-19366-9 33402679
50 Wheeler E, Leong A, Liu CT, et al. Impact of common genetic determinants of hemoglobin A1c on type 2 diabetes risk and diagnosis in ancestrally diverse populations: a transethnic genome-wide meta-analysis. PLoS Med. 2017;14(9):e1002383. doi:10.1371/journal.pmed.1002383 28898252
51 Lagou V, Jiang L, Ulrich A, et al. Random glucose GWAS in 493,036 individuals provides insights into diabetes pathophysiology, complications and treatment stratification. medRxiv. 2021. doi:10.1101/2021.04.17.21255471
52 Below JE, Gamazon ER, Morrison JV, et al. Genome-wide association and meta-analysis in populations from Starr County, Texas, and Mexico City identify type 2 diabetes susceptibility loci and enrichment for expression quantitative trait loci in top signals. Diabetologia. 2011;54(8):2047-2055. doi:10.1007/s00125-011-2188-3 21647700
53 Kooner JS, Saleheen D, Sim X, et al. Genome-wide association study in individuals of South Asian ancestry identifies six new type 2 diabetes susceptibility loci. Nat Genet. 2011;43(10):984-989. doi:10.1038/ng.921 21874001
54 Palmer ND, McDonough CW, Hicks PJ, et al. A genome-wide association search for type 2 diabetes genes in African Americans. PLoS One. 2012;7(1):e29202. doi:10.1371/journal.pone.0029202 22238593
55 Parra EJ, Below JE, Krithika S, et al. Genome-wide association study of type 2 diabetes in a sample from Mexico City and a meta-analysis of a Mexican-American sample from Starr County, Texas. Diabetologia. 2011;54(8):2038-2046. doi:10.1007/s00125-011-2172-y 21573907
56 Shu XO, Long J, Cai Q, et al. Identification of new genetic risk variants for type 2 diabetes. PLoS Genet. 2010;6(9):e1001127. doi:10.1371/journal.pgen.1001127 20862305
57 Tsai FJ, Yang CF, Chen CC, et al. A genome-wide association study identifies susceptibility variants for type 2 diabetes in Han Chinese. PLoS Genet. 2010;6(2):e1000847. doi:10.1371/journal.pgen.1000847 20174558
58 Unoki H, Takahashi A, Kawaguchi T, et al. SNPs in KCNQ1 are associated with susceptibility to type 2 diabetes in East Asian and European populations. Nat Genet. 2008;40(9):1098-1102. doi:10.1038/ng.208 18711366
59 Yamauchi T, Hara K, Maeda S, et al. A genome-wide association study in the Japanese population identifies susceptibility loci for type 2 diabetes at UBE2E2 and C2CD4A-C2CD4B. Nat Genet. 2010;42(10):864-868. doi:10.1038/ng.660 20818381
60 Yasuda K, Miyake K, Horikawa Y, et al. Variants in KCNQ1 are associated with susceptibility to type 2 diabetes mellitus. Nat Genet. 2008;40(9):1092-1097. doi:10.1038/ng.207 18711367
61 Cho YS, Chen CH, Hu C, et al. Meta-analysis of genome-wide association studies identifies eight new loci for type 2 diabetes in east Asians. Nat Genet. 2011;44(1):67-72. doi:10.1038/ng.1019 22158537
62 Go MJ, Hwang JY, Park TJ, et al. Genome-wide association study identifies two novel loci with sex-specific effects for type 2 diabetes mellitus and glycemic traits in a Korean population. Diabetes Metab J. 2014;38(5):375-387. doi:10.4093/dmj.2014.38.5.375 25349825
63 Li H, Gan W, Lu L, et al. A genome-wide association study identifies GRK5 and RASGRP1 as type 2 diabetes loci in Chinese Hans. Diabetes. 2013;62(1):291-298. doi:10.2337/db12-0454 22961080
64 Saxena R, Elbers CC, Guo Y, et al. Large-scale gene-centric meta-analysis across 39 studies identifies type 2 diabetes loci. Am J Hum Genet. 2012;90(3):410-425. doi:10.1016/j.ajhg.2011.12.022 22325160
65 Saxena R, Saleheen D, Been LF, et al. Genome-wide association study identifies a novel locus contributing to type 2 diabetes susceptibility in Sikhs of Punjabi origin from India. Diabetes. 2013;62(5):1746-1755. doi:10.2337/db12-1077 23300278
66 Tabassum R, Chauhan G, Dwivedi OP, et al. Genome-wide association study for type 2 diabetes in Indians identifies a new susceptibility locus at 2q21. Diabetes. 2013;62(3):977-986. doi:10.2337/db12-0406 23209189
67 SIGMA Type 2 Diabetes Consortium, Williams AL, Jacobs SB, et al. Sequence variants in SLC16A11 are a common risk factor for type 2 diabetes in Mexico. Nature. 2014;506(7486):97-101. doi:10.1038/nature12828 24390345
68 Hanson RL, Muller YL, Kobes S, et al. A genome-wide association study in American Indians implicates DNER as a susceptibility locus for type 2 diabetes. Diabetes. 2014;63(1):369-376. doi:10.2337/db13-0416 24101674
69 Hara K, Fujita H, Johnson TA, et al. Genome-wide association study identifies three novel loci for type 2 diabetes. Hum Mol Genet. 2014;23(1):239-246. doi:10.1093/hmg/ddt399 23945395
70 Ng MC, Shriner D, Chen BH, et al. Meta-analysis of genome-wide association studies in African Americans provides insights into the genetic architecture of type 2 diabetes. PLoS Genet. 2014;10(8):e1004517. doi:10.1371/journal.pgen.1004517 25102180
71 Suzuki K, Akiyama M, Ishigaki K, et al. Identification of 28 new susceptibility loci for type 2 diabetes in the Japanese population. Nat Genet. 2019;51(3):379-386. doi:10.1038/s41588-018-0332-4 30718926
72 Adeyemo AA, Zaghloul NA, Chen G, et al. ZRANB3 is an African-specific type 2 diabetes locus associated with beta-cell mass and insulin response. Nat Commun. 2019;10(1):3195. doi:10.1038/s41467-019-10967-7 31324766
73 Wojcik GL, Graff M, Nishimura KK, et al. Genetic analyses of diverse populations improves discovery for complex traits. Nature. 2019;570(7762):514-518. doi:10.1038/s41586-019-1310-4 31217584
74 DIAbetes Genetics Replication and Meta-analysis (DIAGRAM) Consortium, Asian Genetic Epidemiology Network Type 2 Diabetes (AGEN-T2D) Consortium, South Asian Type 2 Diabetes (SAT2D) Consortium, et al. Genome-wide trans-ancestry meta-analysis provides insight into the genetic architecture of type 2 diabetes susceptibility. Nat Genet. 2014;46(3):234-244. doi:10.1038/ng.2897 24509480
75 Polfus LM, Darst BF, Highland H, et al. Genetic discovery and risk characterization in type 2 diabetes across diverse populations. HGG Adv. 2021;2(2):1000029. doi:10.1016/j.xhgg.2021.100029
76 Vujkovic M, Keaton JM, Lynch JA, et al. Discovery of 318 new risk loci for type 2 diabetes and related vascular outcomes among 1.4 million participants in a multi-ancestry meta-analysis. Nat Genet. 2020;52(7):680-691. doi:10.1038/s41588-020-0637-y 32541925
77 Mahajan A, Spracklen CN, Zhang W, et al. Multi-ancestry genetic study of type 2 diabetes highlights the power of diverse populations for discovery and translation. Nat Genet. 2022;54(5):560-572. doi:10.1038/s41588-022-01058-3 35551307
78 Loh M, Zhang W, Ng HK, et al. Identification of genetic effects underlying type 2 diabetes in South Asian and European populations. Commun Biol. 2022;5(1):329. doi:10.1038/s42003-022-03248-5 35393509
79 Mägi R, Horikoshi M, Sofer T, et al. Trans-ethnic meta-regression of genome-wide association studies accounting for ancestry increases power for discovery and improves fine-mapping resolution. Hum Mol Genet. 2017;26(18):3639-3650. doi:10.1093/hmg/ddx280 28911207
80 Hou K, Ding Y, Xu Z, et al. Causal effects on complex traits are similar for common variants across segments of different continental ancestries within admixed individuals. Nat Genet. 2023;55(4):549-558. doi:10.1038/s41588-023-01338-6 36941441
81 Suzuki K, Hatzikotoulas K, Southam L, et al. Multi-ancestry genome-wide study in >2.5 million individuals reveals heterogeneity in mechanistic pathways of type 2 diabetes and complications. medRxiv. 2023. doi:10.1101/2023.03.31.23287839
82 Moltke I, Grarup N, Jørgensen ME, et al. A common Greenlandic TBC1D4 variant confers muscle insulin resistance and type 2 diabetes. Nature. 2014;512(7513):190-193. doi:10.1038/nature13425 25043022
83 Voight BF, Kang HM, Ding J, et al. The Metabochip, a custom genotyping array for genetic studies of metabolic, cardiovascular, and anthropometric traits. PLoS Genet. 2012;8(8):e1002793. doi:10.1371/journal.pgen.1002793 22876189
84 The 1000 Genomes Project Consortium. An integrated map of genetic variation from 1,092 human genomes. Nature. 2012;491(7422):56-65. doi:10.1038/nature11632 23128226
85 McCarthy S, Das S, Kretzschmar W, et al. A reference panel of 64,976 haplotypes for genotype imputation. Nat Genet. 2016;48(10):1279-1283. doi:10.1038/ng.3643 27548312
86 Taliun D, Harris DN, Kessler MD, et al. Sequencing of 53,831 diverse genomes from the NHLBI TOPMed Program. Nature. 2021;590(7845):290-299. doi:10.1038/s41586-021-03205-y 33568819
87 Grove ML, Yu B, Cochran BJ, et al. Best practices and joint calling of the HumanExome BeadChip: the CHARGE Consortium. PLoS One. 2013;8(7):e68095. doi:10.1371/journal.pone.0068095 23874508
88 Pulit SL, Voight BF, de Bakker PIW. Multiethnic genetic association studies improve power for locus discovery. PLoS One. 2010;5(9):e12600. doi:10.1371/journal.pone.0012600 20838612
89 Mahajan A, Wessel J, Willems SM, et al. Refining the accuracy of validated target identification through coding variant fine-mapping in type 2 diabetes. Nat Genet. 2018;50(4):559-571. doi:10.1038/s41588-018-0084-1 29632382
90 SIGMA Type 2 Diabetes Consortium, Estrada K, Aukrust I, et al. Association of a low-frequency variant in HNF1A with type 2 diabetes in a Latino population. JAMA. 2014;311(22):2305-2314. doi:10.1001/jama.2014.6511 24915262
91 Flannick J, Mercader JM, Fuchsberger C, et al. Exome sequencing of 20,791 cases of type 2 diabetes and 24,440 controls. Nature. 2019;570(7759):71-76. doi:10.1038/s41586-019-1231-2 31118516
92 Steinthorsdottir V, Thorleifsson G, Sulem P, et al. Identification of low-frequency and rare sequence variants associated with elevated or reduced risk of type 2 diabetes. Nat Genet. 2014;46(3):294-298. doi:10.1038/ng.2882 24464100
93 Fuchsberger C, Flannick J, Teslovich TM, et al. The genetic architecture of type 2 diabetes. Nature. 2016;536(7614):41-47. doi:10.1038/nature18642 27398621
94 Albrechtsen A, Grarup N, Li Y, et al. Exome sequencing-driven discovery of coding polymorphisms associated with common metabolic phenotypes. Diabetologia. 2013;56(2):298-310. doi:10.1007/s00125-012-2756-1 23160641
95 Flannick J, Thorleifsson G, Beer NL, et al. Loss-of-function mutations in SLC30A8 protect against type 2 diabetes. Nat Genet. 2014;46(4):357-363. doi:10.1038/ng.2915 24584071
96 Backman JD, Li AH, Marcketta A, et al. Exome sequencing and analysis of 454,787 UK Biobank participants. Nature. 2021;599(7886):628-634. doi:10.1038/s41586-021-04103-z 34662886
97 Curtis D. Analysis of rare coding variants in 200,000 exome-sequenced subjects reveals novel genetic risk factors for type 2 diabetes. Diabetes Metab Res Rev. 2022;38(1):e3482. doi:10.1002/dmrr.3482 34216101
98 Deaton AM, Parker MM, Ward LD, et al. Gene-level analysis of rare variants in 379,066 whole exome sequences identifies an association of GIGYF1 loss of function with type 2 diabetes. Sci Rep. 2021;11(1):21565. doi:10.1038/s41598-021-99091-5 34732801
99 Nag A, Dhindsa RS, Mitchell J, et al. Human genetics uncovers MAP3K15 as an obesity-independent therapeutic target for diabetes. Sci Adv. 2022;8(46):eadd5430. doi:10.1126/sciadv.add5430 36383675
100 Li Z, Li X, Zhou H, et al. A framework for detecting noncoding rare-variant associations of large-scale whole-genome sequencing studies. Nat Methods. 2022;19(12):1599-1611. doi:10.1038/s41592-022-01640-x 36303018
101 Wessel J, Majarian TD, Highland HM, et al. Rare non-coding variation identified by large scale whole genome sequencing reveals unexplained heritability of type 2 diabetes. medRxiv. 2020. doi:10.1101/2020.11.13.20221812
102 Schaid DJ, Chen W, Larson NB. From genome-wide associations to candidate causal variants by statistical fine-mapping. Nat Rev Genet. 2018;19(8):491-504. doi:10.1038/s41576-018-0016-z 29844615
103 Carrat GR, Hu M, Nguyen-Tu MS, et al. Decreased STARD10 expression is associated with defective insulin secretion in humans and mice. Am J Hum Genet. 2017;100(2):238-256. doi:10.1016/j.ajhg.2017.01.011 28132686
104 Gaulton KJ, Ferreira T, Lee Y, et al. Genetic fine mapping and genomic annotation defines causal mechanisms at type 2 diabetes susceptibility loci. Nat Genet. 2015;47(12):1415-1425. doi:10.1038/ng.3437 26551672
105 Liu CT, Raghavan S, Maruthur N, et al. Trans-ethnic meta-analysis and functional annotation illuminates the genetic architecture of fasting glucose and insulin. Am J Hum Genet. 2016;99(1):56-75. doi:10.1016/j.ajhg.2016.05.006 27321945
106 Miguel-Escalada I, Bonàs-Guarch S, Cebola I, et al. Human pancreatic islet three-dimensional chromatin architecture provides insights into the genetics of type 2 diabetes. Nat Genet. 2019;51(7):1137-1148. doi:10.1038/s41588-019-0457-0 31253982
107 Thurner M, van de Bunt M, Torres JM, et al. Integration of human pancreatic islet genomic data refines regulatory mechanisms at type 2 diabetes susceptibility loci. eLife. 2018;7:e31977. doi:10.7554/eLife.31977 29412141
108 Viñuela A, Varshney A, van de Bunt M, et al. Genetic variant effects on gene expression in human pancreatic islets and their implications for T2D. Nat Commun. 2020;11(1):4912. doi:10.1038/s41467-020-18581-8 32999275
109 Dornbos P, Singh P, Jang DK, et al. Evaluating human genetic support for hypothesized metabolic disease genes. Cell Metab. 2022;34(5):661-666. doi:10.1016/j.cmet.2022.03.011 35421386
110 Forgetta V, Jiang L, Vulpescu NA, et al. An effector index to predict target genes at GWAS loci. Hum Genet. 2022;141(8):1431-1447. doi:10.1007/s00439-022-02434-z 35147782
111 Chiou J, Zeng C, Cheng Z, et al. Single-cell chromatin accessibility identifies pancreatic islet cell type- and state-specific regulatory programs of diabetes risk. Nat Genet. 2021;53(4):455-466. doi:10.1038/s41588-021-00823-0 33795864
112 Su C, Gao L, May CL, et al. 3D chromatin maps of the human pancreas reveal lineage-specific regulatory architecture of T2D risk. Cell Metab. 2022;34(9):1394-1409.e4. doi:10.1016/j.cmet.2022.08.014 36070683
113 Raulerson CK, Ko A, Kidd JC, et al. Adipose tissue gene expression associations reveal hundreds of candidate genes for cardiometabolic traits. Am J Hum Genet. 2019;105(4):773-787. doi:10.1016/j.ajhg.2019.09.001 31564431
114 Wu Y, Broadaway KA, Raulerson CK, et al. Colocalization of GWAS and eQTL signals at loci with multiple signals identifies additional candidate genes for body fat distribution. Hum Mol Genet. 2019;28(24):4161-4172. doi:10.1093/hmg/ddz263 31691812
115 Fulco CP, Nasser J, Jones TR, et al. Activity-by-contact model of enhancer-promoter regulation from thousands of CRISPR perturbations. Nat Genet. 2019;51(12):1664-1669. doi:10.1038/s41588-019-0538-0 31784727
116 Wesolowska-Andersen A, Zhuo Yu G, Nylander V, et al. Deep learning models predict regulatory variants in pancreatic islets and refine type 2 diabetes association signals. eLife. 2020;9:e51503. doi:10.7554/eLife.51503 31985400
117 Rottner AK, Ye Y, Navarro-Guerrero E, et al. A genome-wide CRISPR screen identifies CALCOCO2 as a regulator of beta cell function influencing type 2 diabetes risk. Nat Genet. 2023;55(1):54-65. doi:10.1038/s41588-022-01261-2 36543916
118 Thomsen SK, Ceroni A, van de Bunt M, et al. Systematic functional characterization of candidate causal genes for type 2 diabetes risk variants. Diabetes. 2016;65(12):3805-3811. doi:10.2337/db16-0361 27554474
119 Chimienti F, Devergnas S, Favier A, Seve M. Identification and cloning of a β-cell-specific zinc transporter, ZnT-8, localized into insulin secretory granules. Diabetes. 2004;53(9):2330-2337. doi:10.2337/diabetes.53.9.2330 15331542
120 Nicolson TJ, Bellomo EA, Wijesekara N, et al. Insulin storage and glucose homeostasis in mice null for the granule zinc transporter ZnT8 and studies of the type 2 diabetes-associated variants. Diabetes. 2009;58(9):2070-2083. doi:10.2337/db09-0551 19542200
121 Pound LD, Sarkar SA, Ustione A, et al. The physiological effects of deleting the mouse SLC30A8 gene encoding zinc transporter-8 are influenced by gender and genetic background. PLoS One. 2012;7(7):e40972. doi:10.1371/journal.pone.0040972 22829903
122 Kleiner S, Gomez D, Megra B, et al. Mice harboring the human SLC30A8 R138X loss-of-function mutation have increased insulin secretory capacity. Proc Natl Acad Sci U S A. 2018;115(32):E7642-E7649. doi:10.1073/pnas.1721418115 30038024
123 Dwivedi OP, Lehtovirta M, Hastoy B, et al. Loss of ZnT8 function protects against diabetes by enhanced insulin secretion. Nat Genet. 2019;51(11):1596-1606. doi:10.1038/s41588-019-0513-9 31676859
124 Rusu V, Hoch E, Mercader JM, et al. Type 2 diabetes variants disrupt function of SLC16A11 through two distinct mechanisms. Cell. 2017;170(1):199-212.e20. doi:10.1016/j.cell.2017.06.011 28666119
125 Huyghe JR, Jackson AU, Fogarty MP, et al. Exome array analysis identifies new loci and low-frequency variants influencing insulin processing and secretion. Nat Genet. 2013;45(2):197-201. doi:10.1038/ng.2507 23263489
126 Eipper BA, Milgram SL, Husten EJ, Yun HY, Mains RE. Peptidylglycine alpha-amidating monooxygenase: a multifunctional protein with catalytic, processing, and routing domains. Protein Sci. 1993;2(4):489-497. doi:10.1002/pro.5560020401 8518727
127 Oyarce AM, Eipper BA. Neurosecretory vesicles contain soluble and membrane-associated monofunctional and bifunctional peptidylglycine alpha-amidating monooxygenase proteins. J Neurochem. 1993;60(3):1105-1114. doi:10.1111/j.1471-4159.1993.tb03261.x 8436961
128 Thomsen SK, Raimondo A, Hastoy B, et al. Type 2 diabetes risk alleles in PAM impact insulin release from human pancreatic β-cells. Nat Genet. 2018;50(8):1122-1131. doi:10.1038/s41588-018-0173-1 30054598
129 Udler MS, McCarthy MI, Florez JC, Mahajan A. Genetic risk scores for diabetes diagnosis and precision medicine. Endocr Rev. 2019;40(6):1500-1520. doi:10.1210/er.2019-00088 31322649
130 Lango H, UK Type 2 Diabetes Genetics Consortium, Palmer CN, et al. Assessing the combined impact of 18 common genetic variants of modest effect sizes on type 2 diabetes risk. Diabetes. 2008;57(11):3129-3135. doi:10.2337/db08-0504 18591388
131 Meigs JB, Shrader P, Sullivan LM, et al. Genotype score in addition to common risk factors for prediction of type 2 diabetes. N Engl J Med. 2008;359(21):2208-2219. doi:10.1056/NEJMoa0804742 19020323
132 Lyssenko V, Jonsson A, Almgren P, et al. Clinical risk factors, DNA variants, and the development of type 2 diabetes. N Engl J Med. 2008;359(21):2220-2232. doi:10.1056/NEJMoa0801869 19020324
133 Vassy JL, Hivert MF, Porneala B, et al. Polygenic type 2 diabetes prediction at the limit of common variant detection. Diabetes. 2014;63(6):2172-2182. doi:10.2337/db13-1663 24520119
134 Hivert MF, Jablonski KA, Perreault L, et al. Updated genetic score based on 34 confirmed type 2 diabetes loci is associated with diabetes incidence and regression to normoglycemia in the Diabetes Prevention Program. Diabetes. 2011;60(4):1340-1348. doi:10.2337/db10-1119 21378175
135 Khera AV, Chaffin M, Aragam KG, et al. Genome-wide polygenic scores for common diseases identify individuals with risk equivalent to monogenic mutations. Nat Genet. 2018;50(9):1219-1224. doi:10.1038/s41588-018-0183-z 30104762
136 Multhaup ML, Kita R, Krock B, et al. The Science Behind 23andMe’s Type 2 Diabetes Report. Updated April 2019. Accessed October 16, 2023. https://permalinks.23andme.com/pdf/23_19-Type2Diabetes_March2019.pdf
137 Dornbos P, Koesterer R, Ruttenburg A, et al. A combined polygenic score of 21,293 rare and 22 common variants improves diabetes diagnosis based on hemoglobin A1C levels. Nat Genet. 2022;54(11):1609-1614. doi:10.1038/s41588-022-01200-1 36280733
138 Goodrich JK, Singer-Berk M, Son R, et al. Determinants of penetrance and variable expressivity in monogenic metabolic conditions across 77,184 exomes. Nat Commun. 2021;12(1):3505. doi:10.1038/s41467-021-23556-4 34108472
139 Mirshahi UL, Colclough K, Wright CF, et al. Reduced penetrance of MODY-associated HNF1A/HNF4A variants but not GCK variants in clinically unselected cohorts. Am J Hum Genet. 2022;109(11):2018-2028. doi:10.1016/j.ajhg.2022.09.014 36257325
140 Oram RA, Patel K, Hill A, et al. A type 1 diabetes genetic risk score can aid discrimination between type 1 and type 2 diabetes in young adults. Diabetes Care. 2016;39(3):337-344. doi:10.2337/dc15-1111 26577414
141 Redondo MJ, Hagopian WA, Oram R, et al. The clinical consequences of heterogeneity within and between different diabetes types. Diabetologia. 2020;63(10):2040-2048. doi:10.1007/s00125-020-05211-7 32894314
142 Dimas AS, Lagou V, Barker A, et al. Impact of type 2 diabetes susceptibility variants on quantitative glycemic traits reveals mechanistic heterogeneity. Diabetes. 2014;63(6):2158-2171. doi:10.2337/db13-0949 24296717
143 Udler MS, Kim J, von Grotthuss M, et al. Type 2 diabetes genetic loci informed by multi-trait associations point to disease mechanisms and subtypes: a soft clustering analysis. PLoS Med. 2018;15(9):e1002654. doi:10.1371/journal.pmed.1002654 30240442
144 DiCorpo D, LeClair J, Cole JB, et al. Type 2 diabetes partitioned polygenic scores associate with disease outcomes in 454,193 individuals across 13 cohorts. Diabetes Care. 2022;45(3):674-683. doi:10.2337/dc21-1395 35085396
145 Kim H, Westerman KE, Smith K, et al. High-throughput genetic clustering of type 2 diabetes loci reveals heterogeneous mechanistic pathways of metabolic disease. Diabetologia. 2023;66(3):495-507. doi:10.1007/s00125-022-05848-6 36538063
146 Laber S, Strobel S, Mercader JM, et al. Discovering cellular programs of intrinsic and extrinsic drivers of metabolic traits using LipocyteProfiler. Cell Genom. 2023;3(7):100346. doi:10.1016/j.xgen.2023.100346 37492099
147 Deutsch AJ, Ahlqvist E, Udler MS. Phenotypic and genetic classification of diabetes. Diabetologia. 2022;65(11):1758-1769. doi:10.1007/s00125-022-05769-4 35953726
148 Mansour Aly D, Dwivedi OP, Prasad RB, et al. Genome-wide association analyses highlight etiological differences underlying newly defined subtypes of diabetes. Nat Genet. 2021;53(11):1534-1542. doi:10.1038/s41588-021-00948-2 34737425
149 Nair ATN, Wesolowska-Andersen A, Brorsson C, et al. Heterogeneity in phenotype, disease progression and drug response in type 2 diabetes. Nat Med. 2022;28(5):982-988. doi:10.1038/s41591-022-01790-7 35534565
150 Ahlqvist E, Storm P, Käräjämäki A, et al. Novel subgroups of adult-onset diabetes and their association with outcomes: a data-driven cluster analysis of six variables. Lancet Diabetes Endocrinol. 2018;6(5):361-369. doi:10.1016/S2213-8587(18)30051-2 29503172
151 Jordan DM, Verbanck M, Do R. HOPS: a quantitative score reveals pervasive horizontal pleiotropy in human genetic variation is driven by extreme polygenicity of human traits and diseases. Genome Biol. 2019;20(1):222. doi:10.1186/s13059-019-1844-7 31653226
152 Beer NL, Tribble ND, McCulloch LJ, et al. The P446L variant in GCKR associated with fasting plasma glucose and triglyceride levels exerts its effect through increased glucokinase activity in liver. Hum Mol Genet. 2009;18(21):4081-4088. doi:10.1093/hmg/ddp357 19643913
153 Gloudemans MJ, Balliu B, Nachun D, et al. Integration of genetic colocalizations with physiological and pharmacological perturbations identifies cardiometabolic disease genes. Genome Med. 2022;14(1):31. doi:10.1186/s13073-022-01036-8 35292083
154 Scott RA, Freitag DF, Li L, et al. A genomic approach to therapeutic target validation identifies a glucose-lowering GLP1R variant protective for coronary heart disease. Sci Transl Med. 2016;8(341):341ra76. doi:10.1126/scitranslmed.aad3744
155 Majithia AR, Flannick J, Shahinian P, et al. Rare variants in PPARG with decreased activity in adipocyte differentiation are associated with increased risk of type 2 diabetes. Proc Natl Acad Sci U S A. 2014;111(36):13127-13132. doi:10.1073/pnas.1410428111 25157153
156 Flannick J, Johansson S, Njølstad PR. Common and rare forms of diabetes mellitus: towards a continuum of diabetes subtypes. Nat Rev Endocrinol. 2016;12(7):394-406. doi:10.1038/nrendo.2016.50 27080136
157 Bonnefond A, Boissel M, Bolze A, et al. Pathogenic variants in actionable MODY genes are associated with type 2 diabetes. Nat Metab. 2020;2(10):1126-1134. doi:10.1038/s42255-020-00294-3 33046911
158 Davies NM, Holmes MV, Davey Smith G. Reading Mendelian randomisation studies: a guide, glossary, and checklist for clinicians. BMJ. 2018;362:k601. doi:10.1136/bmj.k601 30002074
159 Wittemans LBL, Lotta LA, Langenberg C. Prioritising risk factors for type 2 diabetes: causal inference through genetic approaches. Curr Diab Rep. 2018;18(7):40. doi:10.1007/s11892-018-1009-1 29779155
160 Ruth KS, Day FR, Tyrrell J, et al. Using human genetics to understand the disease impacts of testosterone in men and women. Nat Med. 2020;26(2):252-258. doi:10.1038/s41591-020-0751-5 32042192
161 Fall T, Xie W, Poon W, et al. Using genetic variants to assess the relationship between circulating lipids and type 2 diabetes. Diabetes. 2015;64(7):2676-2684. doi:10.2337/db14-1710 25948681
162 White J, Swerdlow DI, Preiss D, et al. Association of lipid fractions with risks for coronary artery disease and diabetes. JAMA Cardiol. 2016;1(6):692-699. doi:10.1001/jamacardio.2016.1884 27487401
163 Ridker PM, Danielson E, Fonseca FAH, et al. Rosuvastatin to prevent vascular events in men and women with elevated C-reactive protein. N Engl J Med. 2008;359(21):2195-2207. doi:10.1056/NEJMoa0807646 18997196
164 Besseling J, Kastelein JJ, Defesche JC, Hutten BA, Hovingh GK. Association between familial hypercholesterolemia and prevalence of type 2 diabetes mellitus. JAMA. 2015;313(10):1029-1036. doi:10.1001/jama.2015.1206 25756439
165 Spracklen CN, Horikoshi M, Kim YJ, et al. Identification of type 2 diabetes loci in 433,540 East Asian individuals. Nature. 2020;582(7811):240-245. doi:10.1038/s41586-020-2263-3 32499647
166 Ge T, Irvin MR, Patki A, et al. Development and validation of a trans-ancestry polygenic risk score for type 2 diabetes in diverse populations. Genome Med. 2022;14(1):70. doi:10.1186/s13073-022-01074-2 35765100
167 Manning AK, LaValley M, Liu CT, et al. Meta-analysis of gene-environment interaction: joint estimation of SNP and SNP x environment regression coefficients. Genet Epidemiol. 2011;35(1):11-18. doi:10.1002/gepi.20546 21181894
168 Yang J, Loos RJ, Powell JE, et al. FTO genotype is associated with phenotypic variability of body mass index. Nature. 2012;490(7419):267-272. doi:10.1038/nature11401 22982992
169 Wang Z, Emmerich A, Pillon NJ, et al. Genome-wide association analyses of physical activity and sedentary behavior provide insights into underlying mechanisms and roles in disease prevention. Nat Genet. 2022;54(9):1332-1344. doi:10.1038/s41588-022-01165-1 36071172
170 Young AI, Wauthier FL, Donnelly P. Identifying loci affecting trait variability and detecting interactions in genome-wide association studies. Nat Genet. 2018;50(11):1608-1614. doi:10.1038/s41588-018-0225-6 30323177
171 Takeuchi F, Isono M, Nabika T, et al. Confirmation of ALDH2 as a major locus of drinking behavior and of its variants regulating multiple metabolic phenotypes in a Japanese population. Circ J. 2011;75(4):911-918. doi:10.1253/circj.cj-10-0774 21372407
172 Tcheandjieu C, Zhu X, Hilliard AT, et al. Large-scale genome-wide association study of coronary artery disease in genetically diverse populations. Nat Med. 2022;28(8):1679-1692. doi:10.1038/s41591-022-01891-3 35915156
173 Klarin D, Lynch J, Aragam K, et al. Genome-wide association study of peripheral artery disease in the Million Veteran Program. Nat Med. 2019;25(8):1274-1279. doi:10.1038/s41591-019-0492-5 31285632
174 Mishra A, Malik R, Hachiya T, et al. Stroke genetics informs drug discovery and risk prediction across ancestries. Nature. 2022;611(7934):115-123. doi:10.1038/s41586-022-05165-3 36180795
175 Stanzick KJ, Li Y, Schlosser P, et al. Discovery and prioritization of variants and genes for kidney function in >1.2 million individuals. Nat Commun. 2021;12(1):4350. doi:10.1038/s41467-021-24491-0 34272381
176 van Zuydam NR, Ladenvall C, Voight BF, et al. Genetic predisposition to coronary artery disease in type 2 diabetes mellitus. Circ Genom Precis Med. 2020;13(6):e002769. doi:10.1161/CIRCGEN.119.002769 33321069
177 O’Connor MJ, Schroeder P, Huerta-Chagoya A, et al. Recessive genome-wide meta-analysis illuminates genetic architecture of type 2 diabetes. Diabetes. 2022;71(3):554-565. doi:10.2337/db21-0545 34862199
178 Kong A, Steinthorsdottir V, Masson G, et al. Parental origin of sequence variants associated with complex diseases. Nature. 2009;462(7275):868-874. doi:10.1038/nature08625 20016592
179 Groop L, Pociot F. Genetics of diabetes—are we missing the genes or the disease? Mol Cell Endocrinol. 2014;382(1):726-739. doi:10.1016/j.mce.2013.04.002 23587769
180 Tavaglione F, Targher G, Valenti L, Romeo S. Human and molecular genetics shed lights on fatty liver disease and diabetes conundrum. Endocrinol Diabetes Metab. 2020;3(4):e00179. doi:10.1002/edm2.179 33102799
181 Florez JC, Burtt N, de Bakker PI, et al. Haplotype structure and genotype-phenotype correlations of the sulfonylurea receptor and the islet ATP-sensitive potassium channel gene region. Diabetes. 2004;53(5):1360-1368. doi:10.2337/diabetes.53.5.1360 15111507
182 Wessel J, Chu AY, Willems SM, et al. Low-frequency and rare exome chip variants associate with fasting glucose and type 2 diabetes susceptibility. Nat Commun. 2015;6:5897. doi:10.1038/ncomms6897 25631608
183 Mahajan A, Sim X, Ng HJ, et al. Identification and functional characterization of G6PC2 coding variants influencing glycemic traits define an effector transcript at the G6PC2-ABCB11 locus. PLoS Genet. 2015;11(1):e1004876. doi:10.1371/journal.pgen.1004876 25625282
184 Froguel P, Vaxillaire M, Sun F, et al. Close linkage of glucokinase locus on chromosome 7p to early-onset non-insulin-dependent diabetes mellitus. Nature. 1992;356(6365):162-164. doi:10.1038/356162a0 1545870
185 Glaser B, Kesavan P, Heyman M, et al. Familial hyperinsulinism caused by an activating glucokinase mutation. N Engl J Med. 1998;338(4):226-230. doi:10.1056/NEJM199801223380404 9435328
186 Ashcroft FM, Lloyd M, Haythorne EA. Glucokinase activity in diabetes: too much of a good thing? Trends Endocrinol Metab. 2023;34(2):119-130. doi:10.1016/j.tem.2022.12.007 36586779
187 Zhu D, Li X, Ma J, et al. Dorzagliatin in drug-naïve patients with type 2 diabetes: a randomized, double-blind, placebo-controlled phase 3 trial. Nat Med. 2022;28(5):965-973. doi:10.1038/s41591-022-01802-6 35551294
188 Kamata K, Mitsuya M, Nishimura T, Eiki J, Nagata Y. Structural basis for allosteric regulation of the monomeric allosteric enzyme human glucokinase. Structure. 2004;12(3):429-438. doi:10.1016/j.str.2004.02.005 15016359
189 Raimondo A, Rees MG, Gloyn AL. Glucokinase regulatory protein: complexity at the crossroads of triglyceride and glucose metabolism. Curr Opin Lipidol. 2015;26(2):88-95. doi:10.1097/MOL.0000000000000155 25692341
190 Florez JC, Pearson ER. A roadmap to achieve pharmacological precision medicine in diabetes. Diabetologia. 2022;65(11):1830-1838. doi:10.1007/s00125-022-05732-3 35748917
191 TODAY Study Group, Zeitler P, Hirst K, et al. A clinical trial to maintain glycemic control in youth with type 2 diabetes. N Engl J Med. 2012;366(24):2247-2256. doi:10.1056/NEJMoa1109333 22540912
192 Kahn SE, Haffner SM, Heise MA, et al. Glycemic durability of rosiglitazone, metformin, or glyburide monotherapy. N Engl J Med. 2006;355(23):2427-2443. doi:10.1056/NEJMoa066224 17145742
193 GoDARTS and UKPDS Diabetes Pharmacogenetics Study Group, Wellcome Trust Case Control Consortium 2, Zhou K, et al. Common variants near ATM are associated with glycemic response to metformin in type 2 diabetes. Nat Genet. 2011;43(2):117-120. doi:10.1038/ng.735 21186350
194 Zhou K, Yee SW, Seiser EL, et al. Variation in the glucose transporter gene SLC2A2 is associated with glycemic response to metformin. Nat Genet. 2016;48(9):1055-1059. doi:10.1038/ng.3632 27500523
195 Li JH, Perry JA, Jablonski KA, et al. Identification of genetic variation influencing metformin response in a multiancestry genome-wide association study in the Diabetes Prevention Program (DPP). Diabetes. 2023;72(8):1161-1172. doi:10.2337/db22-0702 36525397
196 Dawed AY, Yee SW, Zhou K, et al. Genome-wide meta-analysis identifies genetic variants associated with glycemic response to sulfonylureas. Diabetes Care. 2021;44(12):2673-2682. doi:10.2337/dc21-1152 34607834
197 Umapathysivam MM, Araldi E, Hastoy B, et al. Type 2 diabetes risk alleles in peptidyl-glycine alpha-amidating monooxygenase influence GLP-1 levels and response to GLP-1 receptor agonists. medRxiv. 2023. doi:10.1101/2023.04.07.23288197
198 Geng Z, Li Q, Huang R, et al. KCNQ1 variant rs163184 is a potential biomarker of glycemic response to exenatide. Pharmacogenomics. 2022;23(6):355-361. doi:10.2217/pgs-2021-0154 35311356
199 Kyriakidou A, Kyriazou AV, Koufakis T, et al. Clinical and genetic predictors of glycemic control and weight loss response to liraglutide in patients with type 2 diabetes. J Pers Med. 2022;12(3):424. doi:10.3390/jpm12030424 35330424
200 Yu M, Wang K, Liu H, Cao R. GLP1R variant is associated with response to exenatide in overweight Chinese type 2 diabetes patients. Pharmacogenomics. 2019;20(4):273-277. doi:10.2217/pgs-2018-0159 30883264
201 Cromer SJ, Lakhani CM, Mercader JM, et al. Association and interaction of genetics and area-level socioeconomic factors on the prevalence of type 2 diabetes and obesity. Diabetes Care. 2023;46(5):944-952. doi:10.2337/dc22-1954 36787958
202 Marston NA, Kamanu FK, Nordio F, et al. Predicting benefit from evolocumab therapy in patients with atherosclerotic disease using a genetic risk score: results from the FOURIER trial. Circulation. 2020;141(8):616-623. doi:10.1161/CIRCULATIONAHA.119.043805 31707849
203 Graham SE, Clarke SL, Wu KH, et al. The power of genetic diversity in genome-wide association studies of lipids. Nature. 2021;600(7890):675-679. doi:10.1038/s41586-021-04064-3 34887591
204 Evangelou E, Warren HR, Mosen-Ansorena D, et al. Genetic analysis of over 1 million people identifies 535 new loci associated with blood pressure traits. Nat Genet. 2018;50(10):1412-1425. doi:10.1038/s41588-018-0205-x 30224653
205 Yengo L, Sidorenko J, Kemper KE, et al. Meta-analysis of genome-wide association studies for height and body mass index in approximately 700000 individuals of European ancestry. Hum Mol Genet. 2018;27(20):3641-3649. doi:10.1093/hmg/ddy271 30124842

FIGURE 1.

Spectrum of Genetic Variation Contributing to Type 2 Diabetes.

Type 2 diabetes is a polygenic condition, with thousands of variants of different allele frequencies jointly leading to disease development. The plot demonstrates the general relationship that exists between variant allele frequency and effect on disease risk. At one extreme, very rare variation causes monogenic forms of diabetes, which represent a distinct subtype of diabetes that shares overlapping features with type 2 diabetes and is often misdiagnosed as type 2 diabetes. At the other extreme, common genetic variants identified largely through GWAS confer small odds ratios for disease. Variation falling in the middle of the allele frequency spectrum has been more challenging to identify due to very large studies being required for adequate discovery power. GWAS, genome-wide association study.

SOURCE: Original figure constructed by R. J. Kreienkamp and M. S. Udler, using BioRender.com

Line graph showing an inverse relationship between allele variant frequency and effect on diabetes risk. Very rare genetic variants are associated with high odds of monogenic diabetes.

FIGURE 2.

Growth of Genome-Wide Association Studies Across Ancestries and Discovery of Loci Over Time.

The pie charts represent type 2 diabetes GWAS, as specified by the U.S. National Human Genome Research Institute–European Bioinformatics Institute (NHGRI–EBI) GWAS catalogue, as well as additional candidate gene or sequencing studies of note. The x-axis shows the year of publication, whereas the y-axis shows discovery sample size. The inner circles are scaled in proportion to discovery sample size, whereas the outer circles are scaled in proportion to total (discovery + replication) sample size. PubMed identifiers for each study are shown at the base of the figure and are connected to the corresponding circle with a dotted line. Selected type 2 diabetes loci are listed directly above the first reporting study. In the bar chart, significant loci are defined as a p-value of 5x10^-8^, and totals are based on the accumulation of loci that were defined as distinct based on the publications noted in the plot at the end of the calendar year; at the end of 2022, 534 type 2 diabetes distinct intervals (520 autosomes, 14 X-chromosome) were defined. GWAS, genome-wide association study.

SOURCE: Original figure constructed by B. F. Voight

Chronological pie charts showing concurrent growth in discovery of significant loci, G W A S sample size, and G W A S participant diversity between 2000 and 2022.

FIGURE 3.

Genetic Loci Associated With Type 2 Diabetes Are Also Associated With Other Metabolic Traits.

The top associated variants that tag signals at 520 autosomal type 2 diabetes (T2D)-associated loci were used to tabulate the number of signals where the tagged variant demonstrates association with one or more cardiometabolic traits (p<1x10^-3^), including triglycerides (203), systolic blood pressure (204), body mass index (205), or fasting glucose (48). Directionality of the risk allele for type 2 diabetes and cardiometabolic traits was not considered.

SOURCE: Original figure constructed by B. F. Voight

Venn diagram showing the significant overlap of loci associated with type 2 diabetes and four metabolic traits: B M I, triglycerides, systolic blood pressure, and fasting glucose.

FIGURE 4.

The Concept of Gene Burden Testing.

Genes that are important for disease pathology may contain multiple rare functional variants that collectively are associated with altered risk of diabetes. This potential can be formally assessed using exome sequence data from individuals with and without diabetes. Filters can be applied, such as how common the variant is in the population and whether the variant is predicted to alter protein function.

SOURCE: Original figure constructed by A. L. Gloyn, using BioRender.com

Illustration showing that transcription of a greater number of rare functional variants increases the risk for diabetes in a population.

FIGURE 5.

Moving From Variant to Function Using Epigenomics.

Any given GWAS locus is likely to contain multiple potential causal variants that are indistinguishable due to LD. Fine-mapping, particularly in populations that have different LD structures, can be used to reduce the number of potential variants. Variants in a DNA sequence with a presumed functional effect, such as a protein-coding sequence or regulatory annotation in a disease-relevant tissue, are more likely to be the causal variant. The potential for a noncoding variant to be functional can be assessed by integrating DNA sequence data with other types of -omics data, such as chromatin state and gene expression in diabetes-relevant cell types (e.g., islets, adipocytes, hepatocytes, and myocytes). Genes that are influenced by altered regulation can be identified through transcriptomics (cis-eQTLs) and through chromatin capture experiments in disease-relevant cell types. Candidate causal variants and diabetes genes can then be prioritized for validation and functional follow-up in cell and animal models. ATAC-seq, assay for transposase-accessible chromatin using sequencing; eQTL, expression quantitative trait loci; GWAS, genome-wide association study; LD, linkage disequilibrium.

SOURCE: Original figure constructed by A. L. Gloyn, using BioRender.com

Illustration showing the pathway of epigenomic research starting from genetic discovery to functional discovery to experimental follow-up.

FIGURE 6.

Performance of Type 2 Diabetes Polygenic Scores in Diabetes Risk Prediction.

(A) Receiver operating curves for rsPS and gePS in identifying type 2 diabetes patients, using data from Morris et al. (39). Type 2 diabetes gePS (AUROC 0.66; with age and sex AUROC 0.73) demonstrate some improvement over rsPS (AUROC 0.62; with age and sex AUROC 0.72) to predict disease risk. (B) The prevalence of diabetes among individuals at each percentile of type 2 diabetes gePS (on left) is compared to the prevalence of diabetes among carriers of rare clinically significant monogenic diabetes variants (on right), in the same UK Biobank (UKBB) population. The prevalence of diabetes in MODY variant carriers is significantly greater than even the highest percentile of gePS. AUROC, area under the receiver operator characteristic curve; gePS, global extended polygenic score; MODY, maturity-onset diabetes of the young; rsPS, restricted-to-significant polygenic score; T2D, type 2 diabetes.

Panel A – R O C graph showing that G E P S has more success in predicting type 2 diabetes compared to R S P S. Panel B – plots showing that prevalence of diabetes among carriers of monogenic variants is greater at all percentiles of G E P S.

FIGURE 7.

Type 2 Diabetes Loci Can Be Grouped Into Clusters That Appear to Capture Mechanisms of Disease.

GWAS signals for type 2 diabetes are illustrated in a Manhattan plot, using 500,000 random variants (38) graphed according to their chromosomal location on the x-axis and the inverse log p-value for association with type 2 diabetes on the y-axis. Each point indicates a SNP capturing an independent GWAS locus used in clustering by Udler et al. (143). The clusters or “endophenotypes” represent intermediate processes leading to hyperglycemia and type 2 diabetes. GWAS, genome-wide association study; SNP, single nucleotide polymorphism.

SOURCE: Original figure constructed by R. J. Kreienkamp and M. S. Udler, using BioRender.com

Scatterplot showing that insulin-related variants present stronger associations with type 2 diabetes risk, regardless of chromosome variant location.