# Editors

## Jean M. Lawrence, ScD, MPH, MSSA, FACE

Senior Advisor for Diabetes Epidemiology

Division of Diabetes, Endocrinology and Metabolic Diseases

National Institute of Diabetes and Digestive and Kidney Diseases

National Institutes of Health

Bethesda, MD

## Sarah Stark Casagrande, PhD

Senior Epidemiologist

Social & Scientific Systems, Inc. (A DLH Holdings Company)

Silver Spring, MD

## William H. Herman, MD, MPH

Stefan S. Fajans/GlaxoSmithKline Professor of Diabetes

Professor of Internal Medicine, Division of Metabolism, Endocrinology, and Diabetes

Professor of Epidemiology, School of Public Health

University of Michigan

Ann Arbor, MI

## Deborah J. Wexler, MD, MSc

Chief, Massachusetts General Hospital Diabetes Unit

Associate Professor, Harvard Medical School

Boston, MA

## William T. Cefalu, MD

Director, Division of Diabetes, Endocrinology and Metabolic Disease

National Institute of Diabetes and Digestive and Kidney Diseases

National Institutes of Health

Bethesda, MD