# Disability and Diabetes in Adults

## Summary

This article reviews findings from national studies of prevalence in diabetes-related disability, presents new data on contemporary trends in disability among people with diabetes across the United States, summarizes risk factors and mechanisms for the excess disability prevalence associated with diabetes, and reviews evidence that disability may be preventable or modifiable.

Cross-sectional and prospective studies have consistently found that people with diabetes have 50%–90% increased risk of disability, including mobility loss, reduced instrumental activities of daily living (IADL) and activities of daily living (ADL), and work disability. The association of diabetes with increased disability risk is multifactorial, with age, longer diabetes duration, obesity, coronary heart disease, lower extremity complications, depression, and stroke among the most consistently observed factors explaining the difference in disability rates between people with and without diabetes. Additionally, several studies have suggested that specific physiological factors, including inflammation, insulin resistance, hyperglycemia, and their contribution to loss of muscle mass, may also mediate the higher diabetes-related disability risk.

Nationally representative data from 2019–2022 show that 21% of adult women with diabetes (vs. 9% of women without diabetes) and 19% of adult men with diabetes (vs. 7% of men without diabetes) reported any disability. For both women and men with diabetes, the prevalence of any disability increased with age, ranging from ~15% for adults age 20–44 years to ~35%–40% for those age ≥75 years. The relative differences in disability prevalence between persons with versus without diabetes decreased with age. In 2019–2022, one-third of adults with diabetes had mobility disability or some mobility difficulty. Among persons with diabetes, there were substantial differences in disability prevalence according to other sociodemographic factors. Notably, the prevalence of any disability among persons with diabetes living below the poverty threshold (poverty income ratio [PIR] <1.0) was double the prevalence among those living above the poverty threshold (PIR ≥1.0): 34% vs. 17%, respectively. The high prevalence of disability among people with diabetes poses substantial burden to people with diabetes, health care and public health systems, employers, and payors.

Lifestyle interventions focused on achieving weight loss and increasing physical activity are effective for reducing disability and long-term functional decline in people with diabetes. However, further research is needed to determine the impact of preventive care and diabetes management practices, including diabetes treatment and the emergence of new diabetes therapies, on disability risk. Continued surveillance is needed to determine the impact of primary and secondary prevention approaches on disability risk in the coming decades.

## Introduction

Diabetes is a serious threat to the health of the American public due to its growing prevalence, its contribution to cardiovascular and microvascular complications, and its direct negative impact on function and quality of life (1,2). As of 2021, 38.4 million people were living with diabetes in the United States, and that number is estimated to increase to more than 60 million by 2060 (1,3). The prevalence of diabetes has steadily increased with the increasing age of the adult population, and nearly one-third of adults age ≥65 years have diabetes (1). The vast majority of diabetes cases are type 2 diabetes, characterized by progressive loss of pancreatic β-cell insulin secretion, typically in the context of insulin resistance (4). Approximately 5%–10% of people with diabetes have type 1 diabetes and complete insulin deficiency, most often due to autoimmune β-cell destruction. Other types of diabetes, including inherited syndromes, diseases of exocrine pancreatic insufficiency, and drug- or chemical-induced diabetes are less prevalent. Type 2 diabetes is generally preceded by prediabetes, a period of mild hyperglycemia and rising insulin resistance that is intermediate between normal glucose levels and diabetes. In 2021, 97.6 million U.S. adults (38.0% of the U.S. adult population) had prediabetes (1). Prediabetes is strongly associated with progression to type 2 diabetes, with higher rates of progression among individuals with higher glucose levels. Indeed, those with glycated hemoglobin (A1C) between 5.5% (37 mmol/mol) and 6.0% (42 mmol/mol) have a 5-year incidence rate of diabetes between 5% and 25%, while those with A1C between 6.0% and 6.5% (48 mmol/mol) have a 25%–50% chance of developing diabetes (5).

Diabetes and its complications frequently lead to functional impairments and disabilities, often through multiple, coexisting mechanisms (6,7,8). Dysglycemia may directly cause adverse changes in musculature, contributing to gait dysfunction and frailty (9,10). Diabetes also causes disability through the effects of its macrovascular complications (heart disease, stroke, peripheral artery disease) and microvascular complications (neuropathy, retinopathy, kidney disease) and their resulting impact on health and function. Diabetes is associated with mood disorders, cognitive impairment, and dementia disorders, which are themselves major causes of disability. Therefore, disability is both a direct and indirect consequence of diabetes and a valuable index of the collective impact of diabetes on health status for both individuals and populations (11).

The importance of physical disability is heightened by several trends in the diabetes epidemic. While the incidence of diabetes in the United States has declined slightly since 2008, the prevalence of diabetes has increased steadily over this time period (1). This is due to the changing age distribution of the population, which increasingly comprises a larger proportion of older adults (12). The increase in diabetes prevalence, combined with movement of the “baby boom” birth stratum (born between 1945 and 1960) into the age range corresponding to particularly high incidence of diabetes and complications (60–78 years as of 2024), is expected to increase the absolute numbers of persons with diabetes-related disability (3). A longer duration of diabetes and older age are both associated with a higher frequency of diabetes-related complications (13). In addition, there has been a recent increase in the incidence of diabetes among children, adolescents, and young adults (1,14,15) that may translate into many years of disability over their lifespan. This combination of factors is expected to lead to an increased burden of disability over the coming decades, with effects on clinical care and public health systems (6).

Understanding the relationship between diabetes and disability is important from several perspectives. For individuals with diabetes, loss of physical functioning may be more concerning and of greater damage to quality of life than the diagnosis of traditional clinical complications, such as retinopathy and neuropathy (7,16,17). For both people with diabetes and the clinicians who care for them, preventing disability—including impairments, activity limitations, and participation restrictions—could be a key goal of preventive care. First, disability alters the life expectancy and, therefore, the likelihood of benefit from long-term treatments (18,19). Second, the presence of disability makes diabetes self-management more difficult because of the physical and cognitive requirements of such tasks as physical activity, food preparation, taking medications, blood glucose monitoring, administering insulin, and using diabetes technology. Disability can also take a profound emotional, physical, and economic toll on family and caregivers. For employers, disability affects work productivity and health insurance costs. Finally, at the population level, rates and trends in disability are important global indicators of the progress of public health programs toward the goal of increasing the number of healthy years of life and reducing the average number of years of morbidity in the population (11,20,21).

The objectives of this article are to: (1.) summarize the association of diabetes with disability; (2.) identify the key modifiable and nonmodifiable determinants of disability among people with diabetes, along with the key factors explaining the excess disability prevalence among older adults; (3.) describe trends in diabetes-related disability in the United States overall and among key subgroups; and (4.) review evidence that physical disability can be prevented or modified. The estimates presented refer to the combination of persons with type 1 and type 2 diabetes, with most having type 2 diabetes. The content herein is an update of the Diabetes in America, 3rd edition, chapter Diabetes and Disability (22).

## Conceptual Frameworks and Measurement of Disability

Several conceptual frameworks have evolved to define disability in ways that are useful to diverse groups, including the individual, family, health care system, employer, researcher, public health, and economic assessors (23,24,25). These frameworks, which have several aspects in common, have been incorporated into the model described by the International Classification of Functioning, Disability and Health, developed by the World Health Organization (26,27). In this model, disability is an umbrella term encompassing impairments, activity limitations, and restrictions in participation (Figure 1) (26). Disability may arise from physical, cognitive, mental, or developmental impairments. Contextual factors (social, economic, physical environment, or structural barriers to healthcare, including structural racism), interact with health conditions or injuries to lead to body impairments. Impairments affect activities and participation and, in turn, disability.

Both objective and subjective tools and scales to measure capacity for and performance of functioning have been developed for clinical and epidemiologic settings. Multi-item questionnaires and simple physical tests are often used to assess the impact of chronic diseases on disability. The most common questionnaires used in national studies ask about the respondent’s ability to carry out specific activities (23). In addition, objective physical tests can assess the ability to carry out tasks of mobility or daily functioning (21,28).

## Data Sources, Definitions, and Methods

### Sources and Limitations of National Data on Disability and Diabetes

The National Health and Nutrition Examination Survey (NHANES) is a cross-sectional, national probability sample that has been conducted periodically since 1971 and continuously since 1999. This article utilizes NHANES data collected from noninstitutionalized individuals age ≥20 years for the period 2015–2018 to assess current estimates in disability among adults with diabetes. The NHANES questionnaire on disability was included in the 1999–2018 survey cycles but not the next survey cycle. Participants self-reported diagnosed diabetes status, based on the question of “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Disability was self-reported and categorized as vision disability, hearing disability, mobility disability, instrumental activities of daily living (IADL) disability, activities of daily living (ADL) disability, and work disability. Vision disability was defined as being blind or having serious difficulty seeing even when wearing glasses; hearing disability was defined as being deaf or having serious difficulty hearing; mobility disability was defined as self-reporting needing special equipment to walk or having much difficulty or being unable to walk a quarter mile, walk up 10 steps, stoop/crouch/kneel, walk between rooms, stand up from an armless chair, or get in/out of bed. IADLs refer to activities that are not necessary for fundamental functioning but are necessary for independent living, such as doing housework, preparing meals, and managing money. ADLs refer to activities that are necessary for fundamental functioning, such as using an eating utensil and dressing oneself. Participants who reported “a lot of difficulty” or “unable to do” for questionnaire items in each disability category were determined to have disability, with “any disability” defined as having disability in any of the previously listed categories. Disability related to work is also discussed because of its impact on quality of life and effects on families, caregivers, and employers. Work disability was defined as self-reporting limitations that prohibited the ability to work.

An advantage of the NHANES is that the survey includes a health exam in a mobile examination center where laboratory measures are collected. Thus, the NHANES examination includes measurements of body mass index (BMI, kg/m^2^) and laboratory information to determine levels of glycemia using A1C and fasting plasma glucose (FPG), chronic kidney disease (estimated glomerular filtration rate [eGFR] <60 mL/min/1.73 m^2^), and end-stage kidney disease (eGFR <15 mL/min/1.73 m^2^). Participants self-reported demographic characteristics and comorbidities.

The National Health Interview Survey (NHIS), which comprises the majority of data herein, is a cross-sectional household interview survey that uses a complex sampling design and has been conducted annually since 1957. In the NHIS 2019–2022 survey cycles, participants were asked detailed questions about diabetes and disability. Diabetes was determined to be present if a participant answered “yes” to the following question: “Have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” (If female, other than during pregnancy). Disability was measured using the Washington Group Short Set on Functioning (29), which was incorporated into the NHIS starting in 2019. This questionnaire emerged from international efforts to develop feasible measurement tools that produce internationally comparable disability estimates (29). The questionnaire includes questions related to six dimensions (seeing, hearing, walking, self-care, remembering/concentrating, and communication). Respondents are asked to report the level of difficulty with each domain on a 4-point scale: 1. No difficulty, 2. Some difficulty, 3. A lot of difficulty, 4. Cannot do at all. In this article, disability is defined as reporting “a lot of difficulty” or “cannot do at all,” with a separate category for those reporting “some difficulty” (30). Notably, some prior reports categorized responses of “some difficulty” as “impairment.” This definition of impairment was not used in order to align this report with the International Classification of Functioning, Disability and Health framework that defines impairment as a problem in bodily function or structure (26). A composite measure for disability (“any disability”) was based on a reported disability in one or more of the six dimensions. The prevalences of disability and some difficulty were determined across self-reported demographic characteristics and comorbidities.

The national data analyses presented herein report on disability using the NHANES from 2015 through 2018; more recent data use the NHIS from 2019 through 2022. Given the different methodologies used to measure disability in the NHANES and NHIS, overall prevalence estimates are not directly comparable between these datasets. As such, results from the NHANES are described first, followed by results from the NHIS. Additionally, the NHANES and NHIS both surveyed noninstitutionalized persons, which may underestimate the actual prevalence of disability.

### Statistical Methods

Since the NHANES and NHIS use complex survey designs with oversampling of some population subgroups to improve survey representativeness, all estimates except actual sample sizes were weighted to produce nationally representative estimates of the noninstitutionalized population in the United States. Weighted standard errors (SE) are provided for estimates in tables, and weighted 95% confidence intervals (CI) are provided in figures. Percent estimates were considered significantly different if 95% confidence intervals prepared with weighted standard errors did not overlap. The relative standard error (RSE = [SE/estimate]*100) is provided in tables and figures for estimates that are likely unreliable due to small sample size. Estimates with RSEs >50% are censored.

## Association of Diabetes With Limitations and Disabilities in Physical Functioning: Review of Prior Studies

Disability is a major contributor to the high costs associated with diabetes in the United States. Most recent estimates suggest that of the $412.9 billion spent on diabetes in 2022, 26% ($106.3 billion) is attributable to indirect costs associated with lost productivity, unemployment, and premature mortality (31). A 2022 meta-analysis found that adults age ≥65 years with diabetes have a 2.28 years (95% CI 0.57–3.99) lower disability-free life expectancy compared to older adults without diabetes (32). Importantly, loss of disability-free life years in people with diabetes was greater than the loss of overall life expectancy, suggesting that diabetes lengthens the period of disability (32). In a Taiwanese longitudinal study, diabetes accelerated disability during aging by 3 years for mobility disability, 7 years for IADL limitations, and 11 years for ADL limitations (33).

Perhaps the earliest population-based estimates of the association of diabetes with disability in the United States were published in 1960, when the National Center for Health Statistics reported prevalences of diagnosed diabetes and disability due to diabetes based on data from the NHIS 1957–1959 (34). Prevalence of diagnosed diabetes among the overall population was only 0.9% at the time (vs. 14.7% in 2017–2020); among the age group 65–74 years, prevalence was 3% in men and 5% in women (in contrast, more than 29% of adults age ≥65 years had diabetes in 2017–2020) (1,34). Among those with diabetes in 1957–1959, fewer than 10% of women and 7% of men reported any limitation in mobility. Among those age ≥65 years, prevalence of any mobility limitation was 18%. About 20% reported at least one day of restricted activity due to diabetes in the previous year, and 9% reported more than one day in bed in the previous year due to diabetes-associated disability.

Studies using national data published since that early report have described stronger associations of diabetes with disabilities, including associations with a broad spectrum of specific domains and perspectives of disability, such as mobility and IADL. Among adults age ≥20 years with diabetes, the NHANES 2005–2010 revealed the age-standardized prevalence of mobility disability to be 32.0% in women and 17.7% in men (vs. 13.0% and 8.5% in women and men without diabetes, respectively); prevalence of IADL disability to be 8.0% in women and 6.8% in men (vs. 1.8% and 3.8% in women and men without diabetes, respectively); prevalence of ADL disability to be 0.8% in women and 0.9% in men (vs. <0.2% in women and men without diabetes); and prevalence of work disability to be 29.4% in women and 19.3% in men (vs. 9.4% and 8.6% in women and men without diabetes, respectively) (22). These findings were consistent with the literature from the 1990s and early 2000s, with the prevalence of disability across different domains being approximately three to five times higher among people with diabetes compared to those without (35,36,37,38,39,40). Although the absolute prevalence of disability was lower for all indicators among men with diabetes compared to women, the magnitude of association of diabetes with disability was similar for men and women.

These associations of diabetes with self-reported disability were also present for objective physical performance tests. In a study using NHANES data between 1988 and 1994, men with diabetes were twice as likely as men without diabetes to perform poorly on tests of walking speed, 89% more likely to perform poorly on balance tests, and 36% more likely to perform poorly on chair stands, a test of lower extremity function (41). Subsequent analysis of NHIS data between 1997 and 1999 had similar findings. After adjusting for age, sex, and race and ethnicity, diabetes was associated with three times the odds of self-reported limitations in performing nine physical tasks, including walking a quarter mile, climbing stairs, and carrying groceries (42).

Analysis of NHANES 1999–2006 data found associations between diabetes and six domains of disability in U.S. adults age ≥60 years (43): 74% of persons with diabetes reported difficulty (“some difficulty” or greater) in tasks of general physical mobility (e.g., stooping, crouching, standing up), 52% reported difficulty in lower extremity mobility (walking a quarter mile, climbing stairs), 44% reported difficulty in IADLs (e.g., cooking, cleaning), 37% reported difficulty in ADLs (e.g., eating, dressing), and 34% reported difficulty in leisure and social activities (e.g., going out to movies and shopping; leisure activities at home). The odds ratios of disability associated with diabetes ranged from 1.97 for general mobility to 2.53 for ADL. When disability was defined using more severe thresholds—an inability (as opposed to “a lot of difficulty”) to carry out tasks—the odds ratios of disability associated with diabetes were higher, ranging from 2.64 for general mobility to 3.93 for ADL. An analysis of cross-sectional data from the Health, Aging, and Body Composition (Health ABC) Study showed that diabetes was associated with 40% higher odds of functional decline when defined by objective measures, including chair stands, standing balance, and gait speed, in analyses adjusting for age, sex, BMI, and comorbid conditions (44).

A systematic review quantified the association of diabetes and disability from cross-sectional studies conducted between 1996 and 2010, including the U.S. studies described above (8,41,43). Ten studies were conducted in North America, five in Asia, nine in Europe, and one in Australia (8). For the association of diabetes with mobility disability, odds ratios ranged from 1.10 to 2.20, and the pooled odds ratio was 1.68 (95% CI 1.50–1.86). For IADL, odds ratios ranged from 1.20 to 3.30, and the pooled odds ratio was 1.67 (95% CI 1.57–1.77). There was somewhat more heterogeneity for the association of diabetes with ADL disability, as odds ratios ranged from 1.51 to 4.61, and the pooled odds ratio was 1.87 (95% CI 1.66–2.10).

The age at diabetes diagnosis has an important effect on the risk of disability. Analysis of the 1995 to 2018 waves of the Health and Retirement Study (HRS), a nationally representative, biennial, longitudinal health interview survey of U.S. adults age ≥50 years, examined the incidence of disability, measured using self-reported ADL and IADL dependencies (defined as the first year when participants reported dependency in at least 5 of 11 measured ADL and IADL activities), as a function of age at diabetes diagnosis compared to matched controls without diabetes (45). While the incidence of disability increased with age, the incidence risk ratios (IRRs) for the association of each age group at diabetes diagnosis and disability narrowed with increasing age. The association between diabetes and disability was strongest among individuals diagnosed with diabetes at age 50–59 years (IRR 2.03, 95% CI 1.55–2.66) compared to those diagnosed at age 60–69 years (IRR 1.29, 95% CI 1.07–1.55). Those who were diagnosed with diabetes at age ≥70 years had a similar IRR for incident disability as those without diabetes.

Studies of the impact of diabetes on work productivity, absenteeism, and early retirement have found significant differences between adults with and without diabetes (46,47,48,49,50,51,52). Persons with diabetes have about twice the absenteeism rate (5–18 days per year across studies) as those without diabetes (3–9 days per year) (46). In the most extensive study of work productivity, defined as time lost from work or impaired at work due to illness, U.S. adults with diabetes without neuropathy lost an average of 12 days per year, while adults with diabetes complicated by neuropathy lost an average of 26 days per year (52).

More recently, the coronavirus disease of 2019 (COVID-19) pandemic may have worsened the disability experienced among people with diabetes. “Long COVID” or post-acute sequelae of SARS-CoV-2 causes a myriad of health effects in multiple body systems that can potentially result in disability (53). People with diabetes are at increased risk for higher severity COVID-19 illness and death (54); however, whether persons with diabetes are more likely to experience long-term morbidity or disability from long COVID is unknown. Robust data are scarce, but several studies showed no independent association between diabetes and risk of long COVID (55,56). Severity of the COVID-19 infection does increase the risk of long COVID (55,56). In addition, COVID-19 infection may increase the risk for developing new-onset diabetes, potentially increasing diabetes prevalence and burden (57).

## National Estimates of Disability Prevalence

Table 1 provides national estimates of age-adjusted prevalence of disability among adults age ≥20 years with diagnosed diabetes in the NHANES 2015–2018 by key demographic, socioeconomic, and health factors. Figure 2 provides national estimates of disability in the NHANES 2015–2018 according to glycemic status, leveraging the availability of biochemical measures in the NHANES to identify persons with undiagnosed diabetes (A1C ≥6.5% or FPG ≥126 mg/dL [≥6.99 mmol/L]), prediabetes (A1C 5.7%-<6.5% [39–<48 mmol/mol] or FPG 100–125 mg/dL [5.55–6.94 mmol/L]), and normal glucose levels (A1C <5.7% and FPG <100 mg/dL). The questions used to estimate disability through 2018 were not included in the NHANES January 2019–March 2020 or August 2021–August 2023, the most recent phases of the NHANES at the time of this publication. Figure 3 highlights the challenge in comparing disability prevalence estimates and trends in the NHANES 2015–2018 to the NHIS 2019–2022 due to changes in methodology. Because methodologies to ascertain and define disability differed, absolute rates of disability in the NHANES and NHIS are not directly comparable. Figures 4, 5, 6, and 7 and Tables 2, 3, and 4 describe national estimates of disability among persons with diagnosed diabetes in the NHIS 2019–2022 based on the Washington Group Short Set.

### Prevalence of Disability by Glycemic Status, NHANES

Figure 2 shows the age-standardized prevalence of disability according to glycemic status (diagnosed diabetes, undiagnosed diabetes, prediabetes, normoglycemia) among adults in the NHANES 2015–2018 survey cycles. There was a positive association between increasing levels of dysglycemia and prevalence of any disability, with successively higher disability prevalences across those with normal glucose levels (19.7%), prediabetes (22.1%), undiagnosed diabetes (27.1%), and diagnosed diabetes (40.1%). The prevalence estimates for the individual components of any disability (vision, hearing, mobility, IADL, ADL) were highest among persons with diagnosed diabetes. Work disability was highest among persons with diagnosed diabetes (24.7%), followed by persons with undiagnosed diabetes (16.7%), prediabetes (12.8%), and normal glucose levels (10.5%).

### Prevalence of Disability by Sociodemographic Characteristics and Health Factors Among Adults With Diagnosed Diabetes, NHANES

In the NHANES 2015–2018, the age-standardized prevalence of any disability among adults with diagnosed diabetes was 40.1% (Table 1). Among persons with diagnosed diabetes in the NHANES 2015–2018, the prevalence of disability increased substantially with age, ranging from 28.7% among adults age 20–44 years to 82.8% among adults age ≥75 years. The prevalence of any disability was ~35%–40% among persons who self-identified their race and ethnicity as non-Hispanic White, non-Hispanic Black, or Hispanic, whereas the prevalence was 23% among non-Hispanic Asian persons. In persons with diagnosed diabetes, the prevalence of any disability was higher among women compared to men (43.9% vs. 36.3%) and among those with lower educational attainment (53%–58% for less than high school graduate vs. 27% college graduate). The prevalence of any disability was high among persons with Medicaid insurance (62.7%) and persons age ≥65 years with Medicare insurance (67.4%) compared to persons with private insurance (29.6%) and those without health insurance (45.9%). The age-standardized prevalence of disability was inconsistent across categories of diabetes duration. There was a J-shaped association of BMI categories and prevalence of any disability. Prevalence of any disability was substantial among persons with diagnosed diabetes and other comorbidities, particularly those with end-stage kidney disease (88.8%), stroke (72.2%), depression (82.0%), and chronic obstructive pulmonary disease (COPD)/chronic lung disease (69.8%).

### Prevalence of Disability by Age, Sex, and Diabetes Status, NHIS

In the NHIS 2019–2022, the age-standardized prevalence of any disability among adults with diagnosed diabetes was 19.9%. This was substantially lower than the prevalence estimated in the NHANES (40%). The prevalence was stable over time (Figure 3). The age-standardized prevalence of any disability was higher among women (vs. men), regardless of diabetes status, and higher for women and men with diagnosed diabetes versus without diabetes (Tables 2 and 3). Prevalence of any disability among adult women with diabetes was 21.0% compared to 8.5% in women without diabetes (Table 2). The prevalence of any disability among 20–44-year-old women was about 3.3 times that of same-aged women without diabetes (13.8% vs. 4.2%), whereas the prevalence was 1.6 times higher among women age ≥75 years (39.3% vs. 24.8%, with vs. without diabetes, respectively) (Table 2). Among adult men with diabetes, the age-standardized prevalence of any disability was 18.8% compared to 7.1% in men without diabetes (Table 3). The prevalence of any disability was about fivefold higher for men age 20–44 years with diabetes compared to those without diabetes (15.6% vs. 3.4%, respectively), whereas the prevalence was 1.6 times higher among men age ≥75 years (34.3% with diabetes vs. 21.9% without diabetes) (Table 3). For both women and men with diabetes, the prevalence of any disability increased with age, ranging from ~15% for adults age 20–44 years to ~35%–40% for those age ≥75 years (Tables 2 and 3).

In the NHIS 2019–2022, nearly 40% of women and nearly one-third of men with diagnosed diabetes had mobility disability or some mobility difficulty (Tables 2 and 3). The prevalence of mobility disability among adults with diabetes increased with age, ranging from 8% for men and women age 20–44 years to ~25%–30% for those age ≥75 years (Tables 2 and 3). Cognitive disability was the second most common type of disability among people with diabetes, affecting approximately 5% of both women and men; an additional approximately one-third of women and one-fourth of men with diabetes had some cognitive difficulty. Vision disability was also common, with about one-quarter of women and one-fifth of men with diabetes having some vision difficulty or disability.

Between 2019 and 2022, the prevalence of any disability among people with diabetes was stable, with no notable yearly trends (p-linear trend 0.53). There were no significant yearly trends in any disability by categories of age or sex (p-trends>0.4; data not shown). There were also no significant trends in the six disability types overall and by age and sex.

### Prevalence of Disability by Sociodemographic Characteristics and Health Factors Among Adults With Diagnosed Diabetes, NHIS

In the NHIS 2019–2022, among persons with diabetes, substantial differences were observed in disability prevalence by sociodemographic factors (Figures 4, 5, 6, and 7 and Table 4). The age-standardized prevalence of any disability was highest among non-Hispanic White persons (22.5%), followed by non-Hispanic Black (18.2%) and Hispanic (18.0%) persons, with non-Hispanic Asian persons (12.4%) having the lowest prevalence (Figure 4). The prevalence of any disability was higher among persons with less than a high school education (27.1%) compared to those with a high school education (22.4%) or above (15.8%) (Figure 5). Similarly, the prevalence of any disability among persons with a poverty income ratio (PIR) <1.0 was double the prevalence among those with a PIR ≥1.0 (34.0% vs. 17.1%) (Figure 6). The prevalence of any disability was 38.7% for adults with Medicare and 35.1% for Medicaid recipients, whereas the prevalence was 16.7% for those without insurance and 12.4% for those with private insurance (Figure 7). The prevalence of any disability was highest among persons with diabetes duration longer than 15 years (24.4%) compared to those with diabetes duration of 15 years or less. The prevalence of any disability was higher among persons with underweight (BMI <18.5 kg/m^2^; 27.5%) or obesity (BMI ≥30.0 kg/m^2^; 23.6%) compared with those who were normal weight (BMI 18.5–<25.0 kg/m^2^; 14.1%) or with overweight (BMI 25.0–<30.0 kg/m^2^; 14.3%). Nearly one-half (49.0%) of participants with diabetes and COPD reported any disability, with 37.6% reporting mobility disability (Table 4).

Of the individual disability components, mobility disability was the most commonly reported disability (13.3%) (Table 4). The total prevalence estimates of the other disability types ranged from 1.4% for communication disability to 5.0% for cognitive disability. The burden of the individual disability types generally followed a similar pattern across sociodemographic characteristics and health factors to those found for any disability (Table 4). The age-standardized prevalence of vision disability was 6% among persons with a diabetes duration greater than 15 years, while the prevalence estimates of vision disability among persons with shorter diabetes duration (<2 years, 2–5 years, and 6–15 years) were all ~3% (Table 4). Mobility disability was also higher for persons with a duration of diabetes greater than 15 years compared to shorter disease durations.

## Factors Explaining the Association of Diabetes With Disability

Several studies have attempted to determine the mechanisms whereby diabetes mediates increased disability risk. This research has been conducted using two primary approaches: (1.) adding potential mediators to statistical models of the effect of diabetes on disability and examining for attenuation of the diabetes to disability association (41,58,59,60,61,62); and (2.) examining the effect of diabetes on pathophysiologic processes known to mediate disability (9,10,60,63,64,65). There is also a large body of research modeling the contribution of diabetes to the population burden of associated chronic conditions and diabetes complications, which helps clarify the total magnitude of disability resulting from diabetes. These conditions include cardiovascular disease (66,67), peripheral neuropathy and amputation (68,69,70), diabetic retinopathy (71,72), chronic kidney disease (73,74,75,76), stroke and neurovascular conditions (60,77), and psychiatric disorders (78,79). These conditions may lead to disability through disease-specific mechanisms or, as in the case of vision impairment due to diabetic retinopathy, are themselves disability subtypes. Overall, these various approaches to explaining how diabetes contributes to disability examine different facets of a complex relationship between direct effects of glycemia on organ dysfunction, indirect effects on chronic health conditions, and disability (80).

Analyses of mediators of the relationship between diabetes and disability have primarily used older, cross-sectional data from large cohort studies or national surveys. A mediation analysis using data from the NHANES III (1988–1994) found that coronary heart disease (CHD) and obesity together explained more than one-half of the excess disability risk associated with diabetes among women. Among men, CHD and stroke were the two most dominant factors (41,80). Several other factors, including stroke, visual impairment, and arthritis, played significant roles in both men and women. Subsequent analyses using the Women’s Health and Aging Study found peripheral arterial disease, peripheral nerve dysfunction, and depression were important mediators of disability in diabetes (59).

A growing body of literature is evaluating the direct effect of chronic hyperglycemia on pathophysiologic processes underlying disability. Sarcopenia, or the natural loss of muscle mass that occurs with aging, may be a central mechanism in this process. Hyperinsulinemia, insulin resistance, hyperglycemia, and a longer duration of diabetes have each been associated with sarcopenia (63,81). The association of diabetes with sarcopenia may be multifactorial, as behavioral factors (physical inactivity and reduced energy expenditure), central adiposity and resulting inflammatory factors, hormonal changes (e.g., hypogonadism, vitamin D deficiency), and comorbid conditions (e.g., kidney disease, peripheral artery disease) could connect diabetes to sarcopenia (81). A study using data from the NHANES 2011–2014 found that muscle quality is impaired even among individuals with prediabetes, and this relationship is mediated in large part by insulin resistance (82).

A number of other studies have examined the association between diabetes and frailty, a condition that often overlaps with sarcopenia, which is characterized by physical decline with fatigue, weight loss, muscle weakness, and gait dysfunction (25). A systematic review found that having diabetes increases the odds of incident frailty by 50%, and frailty among those with diabetes is associated with a higher risk of complications and mortality (10). It is important to note that the relationship between glycemia and frailty is not linear, and both higher and lower A1C levels are found to be associated with frailty in people with diabetes (9). It is likely that there are multiple distinct phenotypes of frailty in people with diabetes, including individuals with high A1C and resultant sarcopenia, and individuals who become ill or malnourished, leading to both frailty and low A1C levels (9). The relationship between diabetes and frailty is likely bidirectional, as there is evidence that physical and cognitive disabilities in people with diabetes causes these individuals to engage in less physical activity, which can lead to worsening strength and mobility (62). Hypoglycemia caused by diabetes treatment has also been associated with frailty in several studies, although the direction of this effect is unclear (9,83). The impact of diabetes pharmacotherapy on sarcopenia and frailty requires further study.

In summary, these studies found the relationship between diabetes and disability to be multifactorial with complex, and sometimes bidirectional, mechanisms. Obesity, CHD, lower extremity complications, stroke, and depression appear to be prominent factors explaining the difference in disability risk between people with and without diabetes. Factors early in the pathogenesis of diabetes, including inflammation and insulin resistance, may cause sarcopenia and frailty that may mediate the higher disability risk in people with diabetes. Volpato and Maraldi organized explanatory factors into a conceptual model wherein diabetes interacts in a bidirectional manner with obesity, CHD, hypertension, stroke, and depression to influence several primary impairments, including visual acuity, peripheral neuropathy, cognitive function, and strength, which combined with underlying comorbidities, lead to functional limitations and disabilities (84).

## Disability and Diabetes Risk

Epidemiologic studies of diabetes and disability have primarily been conducted to examine the potential for diabetes to cause disability. However, the association could act in the reverse direction, with disability increasing the risk of diabetes, particularly among high-risk adults. In a longitudinal analysis of data from 22,878 middle-aged and older adults, prevalent mild disability was associated with a 28% increased risk of diabetes incidence, while incident mild disability was associated with a 40% increased diabetes risk (85). More severe disability was associated with an even higher magnitude of diabetes risk (63% for prevalent disability and 81% for incident disability). The authors speculated that disability could contribute to diabetes risk through increases in sedentary behavior and change in the ratio of lean to fat mass, affecting insulin sensitivity in vulnerable adults. Supportive of this hypothesis are data from individuals with chronic spinal cord injury, who often develop increased insulin resistance and have higher rates of incident diabetes compared to the general population (86). Further, a large cohort study of adults age ≥55 years in Canada found that adults with lower extremity osteoarthritis, especially hip osteoarthritis, had a modestly increased risk for incident diabetes (25% higher hazard ratio comparing two vs. no affected hips), which was in part explained by mobility limitations (87).

## Effectiveness of Interventions to Reduce Disability Risk

Only a few controlled intervention trials have examined the effectiveness of approaches to reduce disability among adults with diabetes or at risk for diabetes. Studies conducted among adults (with and without diabetes) with arthritis-mediated functional impairment found that lifestyle-based weight loss of 5%–6% over 18 months resulted in significant improvements in functional status (88,89). Similar effects have been reported in adults with CHD and preexisting functional limitations (90,91). The Look AHEAD (Action for Health in Diabetes) study is the largest intervention trial to date to examine the effects of lifestyle change on disability and the first large study of its kind among adults with diabetes. Look AHEAD randomized adults with type 2 diabetes and overweight or obesity to an intensive lifestyle intervention aimed at achieving weight loss through calorie restriction and increased physical activity or diabetes support and education. Look AHEAD had several key findings related to disability. At 4 years of follow-up, persons in the intensive lifestyle intervention arm had a 48% lower odds of mobility-related disability (92). The prevalence of severe mobility disability at 4 years follow-up was 21% in the intensive lifestyle intervention and 26% in the control arm. Over 10 years of follow-up, the intensive lifestyle intervention resulted in a 0.8–0.9-year delay in the onset of moderate to severe physical disability (93). A subset of Look AHEAD participants underwent objective performance testing using the Short Physical Performance Battery that demonstrated benefits of the intensive lifestyle intervention on physical function at 8- and 11-years follow-up (94,95).

In addition to lifestyle intervention, achieving evidence-based goals for glucose lowering and management of cardiovascular risk factors is likely to prevent disability among people with diabetes by preventing complications (43). Further, the risk and/or impact of disability among people with diabetes may be mitigated by addressing social isolation (96,97,98,99), supporting physical activity (97,100) and other healthy behaviors (98), and addressing depressive symptoms (101). For example, a large observational cohort study in Sweden found that a healthy lifestyle profile characterized by physically active leisure activities, avoidance of tobacco or heavy alcohol use, and being in the middle or upper tertile of a social connectivity index was associated with a 3-year longer disability-free survival among adults with diabetes (98).

It is also important to note the large potential benefits of diabetes prevention on reducing the burden of disability. Interventional studies, including the Diabetes Prevention Program, established that lifestyle intervention and, to a lesser extent, metformin therapy are effective at reducing diabetes incidence over 15 years or longer (102,103). A modeling analysis using data from England and Wales found that decreasing the incidence of diabetes over the next four decades could result in dramatic reductions in moderate to severe disability, dementia, and mortality (104).

Finally, disability risk may be modifiable by treatment with newer diabetes medications, especially glucagon-like peptide-1 (GLP-1) receptor agonists that induce weight loss and have cardiovascular and kidney benefits and sodium-glucose cotransporter-2 (SGLT2) inhibitors that have cardiovascular and kidney benefits, including on symptomatic heart failure (105). The GLP-1 receptor agonist semaglutide was found to improve symptoms and decrease physical limitations among people with type 2 diabetes and obesity-related heart failure (106). More research is needed to evaluate the changing landscape of diabetes pharmacotherapy and its effects on disability.

Given the high prevalence of disability among people with diabetes and the potential for mitigating disability through intervention, it is important for clinicians to understand how disability impacts the activities or function of the people with diabetes they care for. Diabetes guidelines recommend that an assessment of disability should be conducted at every clinic visit for people with diabetes (107).

## Conclusions

Diabetes is associated with a twofold to threefold increased risk of functional disability, including disability related to mobility, IADL, ADL, and work. Longitudinal studies indicate that diabetes precedes the onset of disability in many cases, but that the diabetes and disability association is also bidirectional. Among persons with diabetes, disability is most common among women and persons of lower education and socioeconomic status (PIR <1.0) and increases rapidly with age. The relative associations of diabetes (vs. no diabetes) with disability are highest among middle-aged adults. The age-standardized prevalence of any disability in persons with diabetes is ~20% in both men and women. This prevalence estimate was unchanged across the individual survey cycles between 2019 to 2022.

The association of diabetes with disability is explained by multiple factors, including some that precede diabetes diagnosis as part of the pathogenesis of diabetes (e.g., obesity, insulin resistance, systemic inflammation), hyperglycemia itself, diabetes-related complications (e.g., CHD, lower extremity arterial disease, stroke, visual impairment), and other comorbidities that may or may not be caused by diabetes (notably, depression and arthritis). Intensive lifestyle interventions that involve regular physical activity and weight loss appear to be effective in reducing risk for disability among adults with diabetes and overweight or obesity. Interventions to prevent diabetes and primary care-based management of depression and cardiovascular disease risk could also plausibly affect disability risk, but this hypothesis has not been examined in randomized controlled trials.

Continued surveillance of disability levels is important to determine whether clinical and public health approaches are reducing the collective impact of diabetes on morbidity. Inclusion of older adults and mobility and disability outcomes in future clinical trials will be important to improve the evidence base about which interventions reduce disability.

## List of Abbreviations

A1C: glycated hemoglobin
ADL: activities of daily living
BMI: body mass index
CHD: coronary heart disease
CI: confidence interval
COPD: chronic obstructive pulmonary disease
COVID-19: coronavirus disease of 2019
FPG: fasting plasma glucose
IADL: instrumental activities of daily living
IRR: incidence risk ratio
Look AHEAD: Action for Health in Diabetes
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
PIR: poverty income ratio

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Glucose: mg/dL x 0.0555 = mmol/L

## Acknowledgment

This is an update of: Gregg EW, Menke A. Diabetes and Disability. Chapter 34 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 34.1–34.15.

## Article History

Received in final form on September 9, 2024.

## References

1 National Diabetes Statistics Report [Internet]. Centers for Disease Control and Prevention;2024. https://www.cdc.gov/diabetes/php/data-research/index.html
2 Sun H, Saeedi P, Karuranga S, et al. IDF Diabetes Atlas: global, regional and country-level diabetes prevalence estimates for 2021 and projections for 2045. Diabetes Res Clin Pract. 2022;183:109119. doi:10.1016/j.diabres.2021.109119 34879977
3 Lin J, Thompson TJ, Cheng YJ, et al. Projection of the future diabetes burden in the United States through 2060. Popul Health Metr. 2018;16(1):9. doi:10.1186/s12963-018-0166-4 29903012
4 American Diabetes Association Professional Practice Committee. 2. Diagnosis and Classification of Diabetes: Standards of Care in Diabetes—2024. Diabetes Care. 2024;47(Suppl 1):S20-S42. doi:10.2337/dc24-S002 38078589
5 Zhang X, Gregg EW, Williamson DF, et al. A1C level and future risk of diabetes: a systematic review. Diabetes Care. 2010;33(7):1665-1673. doi:10.2337/dc09-1939 20587727
6 Caspersen CJ, Thomas GD, Boseman LA, Beckles GL, Albright AL. Aging, diabetes, and the public health system in the United States. Am J Public Health. 2012;102(8):1482-1497. doi:10.2105/AJPH.2011.300616 22698044
7 Phelan EA, Anderson LA, LaCroix AZ, Larson EB. Older adults’ views of “successful aging”—how do they compare with researchers’ definitions? J Am Geriatr Soc. 2004;52(2):211-216. doi:10.1111/j.1532-5415.2004.52056.x 14728629
8 Wong E, Backholer K, Gearon E, et al. Diabetes and risk of physical disability in adults: a systematic review and meta-analysis. Lancet Diabetes Endocrinol. 2013;1(2):106-114. doi:10.1016/S2213-8587(13)70046-9 24622316
9 Abdelhafiz AH, Sinclair AJ. Metabolic phenotypes explain the relationship between dysglycaemia and frailty in older people with type 2 diabetes. J Diabetes Complications. 2022;36(4):108144. doi:10.1016/j.jdiacomp.2022.108144 35151546
10 Hanlon P, Fauré I, Corcoran N, et al. Frailty measurement, prevalence, incidence, and clinical implications in people with diabetes: a systematic review and study-level meta-analysis. Lancet Healthy Longev. 2020;1(3):e106-e116. doi:10.1016/S2666-7568(20)30014-3 33313578
11 Crimmins EM. Trends in the health of the elderly. Annu Rev Public Health. 2004;25:79-98. doi:10.1146/annurev.publhealth.25.102802.124401 15015913
12 Blakeslee L, Caplan Z, Meyer JA, Rabe MA, Roberts AW. Age and sex composition: 2020. U.S. Census Bureau;2023. 2020 Census Briefs;C2020BR-06. https://www2.census.gov/library/publications/decennial/2020/census-briefs/c2020br-06.pdf
13 Huang ES, Laiteerapong N, Liu JY, John PM, Moffet HH, Karter AJ. Rates of complications and mortality in older patients with diabetes mellitus: the Diabetes and Aging Study. JAMA Intern Med. 2014;174(2):251-258. doi:10.1001/jamainternmed.2013.12956 24322595
14 Lawrence JM, Divers J, Isom S, et al. Trends in prevalence of type 1 and type 2 diabetes in children and adolescents in the US, 2001–2017. JAMA. 2021;326(8):717-727. doi:10.1001/jama.2021.11165 34427600
15 Wagenknecht LE, Lawrence JM, Isom S, et al. Trends in incidence of youth-onset type 1 and type 2 diabetes in the USA, 2002–18: results from the population-based SEARCH for Diabetes in Youth study. Lancet Diabetes Endocrinol. 2023;11(4):242-250. doi:10.1016/S2213-8587(23)00025-6 36868256
16 Heisler M, Vijan S, Anderson RM, Ubel PA, Bernstein SJ, Hofer TP. When do patients and their physicians agree on diabetes treatment goals and strategies, and what difference does it make? J Gen Intern Med. 2003;18(11):893-902. doi:10.1046/j.1525-1497.2003.21132.x 14687274
17 Lawton MP, Brody EM. Assessment of older people: self-maintaining and instrumental activities of daily living. Gerontologist. 1969;9(3):179-186. doi:10.1093/geront/9.3_Part_1.179 5349366
18 Huang ES, Zhang Q, Gandra N, Chin MH, Meltzer DO. The effect of comorbid illness and functional status on the expected benefits of intensive glucose control in older patients with type 2 diabetes: a decision analysis. Ann Intern Med. 2008;149(1):11-19. doi:10.7326/0003-4819-149-1-200807010-00005 18591633
19 Pilla SJ, Schoenborn NL, Maruthur NM, Huang ES. Approaches to risk assessment among older patients with diabetes. Curr Diab Rep. 2019;19(8):59. doi:10.1007/s11892-019-1172-z 31324995
20 Fries JF. Measuring and monitoring success in compressing morbidity. Ann Intern Med. 2003;139(5 Pt 2):455-459. doi:10.7326/0003-4819-139-5_part_2-200309021-00015 12965976
21 Guralnik JM, Fried LP, Salive ME. Disability as a public health outcome in the aging population. Annu Rev Public Health. 1996;17:25-46. doi:10.1146/annurev.pu.17.050196.000325 8724214
22 Gregg EW, Menke A. Diabetes and disability. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018; 34.1-34.15:chap 34. https://www.ncbi.nlm.nih.gov/books/NBK567983/
23 Katz S, Ford AB, Moskowitz RW, Jackson BA, Jaffe MW. Studies of illness in the aged. The Index of ADL: a standardized measure of biological and psychosocial function. JAMA. 1963;185(12):914-919. doi:10.1001/jama.1963.03060120024016 14044222
24 Ware J, Jr., Kosinski M, Keller SD. A 12-Item Short-Form Health Survey: construction of scales and preliminary tests of reliability and validity. Med Care. 1996;34(3):220-233. doi:10.1097/00005650-199603000-00003 8628042
25 Fried LP, Tangen CM, Walston J, et al. Frailty in older adults: evidence for a phenotype. J Gerontol A Biol Sci Med Sci. 2001;56(3):M146-M156. doi:10.1093/gerona/56.3.m146 11253156
26 World Health Organization. Towards a common language for functioning, disability and health: ICF, The International Classification of Functioning, Disability and Health. Updated 2002. https://cdn.who.int/media/docs/default-source/classification/icf/icfbeginnersguide.pdf
27 Almansa J, Ayuso-Mateos JL, Garin O, et al. The International Classification of Functioning, Disability and Health: development of capacity and performance scales. J Clin Epidemiol. 2011;64(12):1400-1411. doi:10.1016/j.jclinepi.2011.03.005 21669511
28 Reuben DB, Seeman TE, Keeler E, et al. Refining the categorization of physical functional status: the added value of combining self-reported and performance-based measures. J Gerontol A Biol Sci Med Sci. 2004;59(10):1056-1061. doi:10.1093/gerona/59.10.m1056 15528778
29 The Washington Group. International Measurement of Disability: Purpose, Method and Application. Social Indicators Research Series, vol 61. Springer; 2016. https://link.springer.com/book/10.1007/978-3-319-28498-9
30 Hanass-Hancock J, Kamalakannan S, Murthy GVS, et al. What cut-off(s) to use with the Washington Group Short Set of questions? Disabil Health J. 2023;16(4):101499. doi:10.1016/j.dhjo.2023.101499 37481353
31 Parker ED, Lin J, Mahoney T, et al. Economic costs of diabetes in the U.S. in 2022. Diabetes Care. 2024;47(1):26-43. doi:10.2337/dci23-0085 37909353
32 Lourida I, Bennett HQ, Beyer F, Kingston A, Jagger C. The impact of long-term conditions on disability-free life expectancy: a systematic review. PLoS Glob Public Health. 2022;2(8):e0000745. doi:10.1371/journal.pgph.0000745 36962577
33 Tsai YH, Chuang LL, Lee YJ, Chiu CJ. How does diabetes accelerate normal aging? An examination of ADL, IADL, and mobility disability in middle-aged and older adults with and without diabetes. Diabetes Res Clin Pract. 2021;182:109114. doi:10.1016/j.diabres.2021.109114 34756960
34 U.S. National Health Survey. Health statistics from the U.S. National Health Survey, Diabetes reported in interviews, United States July 1957–June 1959. U.S. Department of Health, Education, and Welfare;1960. Public Health Service Publication No. 584-B21. https://www.cdc.gov/nchs/data/public_health/seriesb_21.pdf
35 Songer T. Disability in diabetes. In: Harris MI, Cowie CC, Stern MP, Boyko EJ, Reiber GE, Bennett PH, eds. Diabetes in America. 2nd ed. National Institutes of Health;1995:259–282:chap 12.
36 Black SA, Ray LA, Markides KS. The prevalence and health burden of self-reported diabetes in older Mexican Americans: findings from the Hispanic Established Populations for Epidemiologic Studies of the Elderly. Am J Public Health. 1999;89(4):546-552. doi:10.2105/ajph.89.4.546 10191799
37 Boult C, Kane RL, Louis TA, Boult L, McCaffrey D. Chronic conditions that lead to functional limitation in the elderly. J Gerontol. 1994;49(1):M28-M36. doi:10.1093/geronj/49.1.m28 8282978
38 Guccione AA, Felson DT, Anderson JJ, et al. The effects of specific medical conditions on the functional limitations of elders in the Framingham Study. Am J Public Health. 1994;84(3):351-358. doi:10.2105/ajph.84.3.351 8129049
39 Moritz DJ, Ostfeld AM, Blazer D, 2nd, Curb D, Taylor JO, Wallace RB. The health burden of diabetes for the elderly in four communities. Public Health Rep. 1994;109(6):782-790.7800788
40 Strawbridge WJ, Cohen RD, Shema SJ, Kaplan GA. Successful aging: predictors and associated activities. Am J Epidemiol. 1996;144(2):135-141. doi:10.1093/oxfordjournals.aje.a008900 8678044
41 Gregg EW, Beckles GL, Williamson DF, et al. Diabetes and physical disability among older U.S. adults. Diabetes Care. 2000;23(9):1272-1277. doi:10.2337/diacare.23.9.1272 10977018
42 Ryerson B, Tierney EF, Thompson TJ, et al. Excess physical limitations among adults with diabetes in the U.S. population, 1997–1999. Diabetes Care. 2003;26(1):206-210. doi:10.2337/diacare.26.1.206 12502682
43 Kalyani RR, Saudek CD, Brancati FL, Selvin E. Association of diabetes, comorbidities, and A1C with functional disability in older adults: results from the National Health and Nutrition Examination Survey (NHANES), 1999–2006. Diabetes Care. 2010;33(5):1055-1060. doi:10.2337/dc09-1597 20185736
44 De Rekeneire N, Resnick HE, Schwartz AV, et al. Diabetes is associated with subclinical functional limitation in nondisabled older individuals: the Health, Aging, and Body Composition study. Diabetes Care. 2003;26(12):3257-3263. doi:10.2337/diacare.26.12.3257 14633811
45 Cigolle CT, Blaum CS, Lyu C, Ha J, Kabeto M, Zhong J. Associations of age at diagnosis and duration of diabetes with morbidity and mortality among older adults. JAMA Netw Open. 2022;5(9):e2232766. doi:10.1001/jamanetworkopen.2022.32766 36178688
46 Breton MC, Guénette L, Amiche MA, Kayibanda JF, Grégoire JP, Moisan J. Burden of diabetes on the ability to work: a systematic review. Diabetes Care. 2013;36(3):740-749. doi:10.2337/dc12-0354 23431092
47 Cawley J, Rizzo JA, Haas K. The association of diabetes with job absenteeism costs among obese and morbidly obese workers. J Occup Environ Med. 2008;50(5):527-534. doi:10.1097/JOM.0b013e31816ed029 18469621
48 De Backer G, Leynen F, De Bacquer D, Clays E, Moreau M, Kornitzer M. Diabetes mellitus in middle-aged people is associated with increased sick leave: the BELSTRESS study. Int J Occup Environ Health. 2006;12(1):28-34. doi:10.1179/oeh.2006.12.1.28 16523980
49 Fu AZ, Qiu Y, Radican L, Wells BJ. Health care and productivity costs associated with diabetic patients with macrovascular comorbid conditions. Diabetes Care. 2009;32(12):2187-2192. doi:10.2337/dc09-1128 19729528
50 Vamos EP, Mucsi I, Keszei A, Kopp MS, Novak M. Comorbid depression is associated with increased healthcare utilization and lost productivity in persons with diabetes: a large nationally representative Hungarian population survey. Psychosom Med. 2009;71(5):501-507. doi:10.1097/PSY.0b013e3181a5a7ad 19528291
51 Tunceli K, Bradley CJ, Nerenz D, Williams LK, Pladevall M, Elston Lafata J. The impact of diabetes on employment and work productivity. Diabetes Care. 2005;28(11):2662-2667. doi:10.2337/diacare.28.11.2662 16249536
52 Stewart WF, Ricci JA, Chee E, Hirsch AG, Brandenburg NA. Lost productive time and costs due to diabetes and diabetic neuropathic pain in the US workforce. J Occup Environ Med. 2007;49(6):672-679. doi:10.1097/JOM.0b013e318065b83a 17563611
53 National Academies of Sciences, Engineering, Medicine. Long-Term Health Effects of COVID-19: Disability and Function Following SARS-CoV-2 Infection. The National Academies Press; 2024. https://nap.nationalacademies.org/catalog/27756/long-term-health-effects-of-covid-19-disability-and-function
54 Hartmann-Boyce J, Rees K, Perring JC, et al. Risks of and from SARS-CoV-2 infection and COVID-19 in people with diabetes: a systematic review of reviews. Diabetes Care. 2021;44(12):2790-2811. doi:10.2337/dc21-0930 34711637
55 Bonner C, Ghouralal SL. Long COVID and chronic conditions in the US workforce: prevalence, productivity loss, and disability. J Occup Environ Med. 2024;66(3):e80-e86. doi:10.1097/JOM.0000000000003026 38083801
56 Chen C, Haupert SR, Zimmermann L, Shi X, Fritsche LG, Mukherjee B. Global prevalence of post-coronavirus disease 2019 (COVID-19) condition or long COVID: a meta-analysis and systematic review. J Infect Dis. 2022;226(9):1593-1607. doi:10.1093/infdis/jiac136 35429399
57 Shrestha DB, Budhathoki P, Raut S, et al. New-onset diabetes in COVID-19 and clinical outcomes: a systematic review and meta-analysis. World J Virol. 2021;10(5):275-287. doi:10.5501/wjv.v10.i5.275 34631477
58 Volpato S, Blaum C, Resnick H, Ferrucci L, Fried LP, Guralnik JM. Comorbidities and impairments explaining the association between diabetes and lower extremity disability: the Women’s Health and Aging Study. Diabetes Care. 2002;25(4):678-683. doi:10.2337/diacare.25.4.678 11919124
59 Volpato S, Ferrucci L, Blaum C, et al. Progression of lower-extremity disability in older women with diabetes: the Women’s Health and Aging Study. Diabetes Care. 2003;26(1):70-75. doi:10.2337/diacare.26.1.70 12502660
60 Geijselaers SLC, Sep SJS, Stehouwer CDA, Biessels GJ. Glucose regulation, cognition, and brain MRI in type 2 diabetes: a systematic review. Lancet Diabetes Endocrinol. 2015;3(1):75-89. doi:10.1016/S2213-8587(14)70148-2 25163604
61 Shang Y, Fratiglioni L, Vetrano DL, Dove A, Welmer AK, Xu W. Not only diabetes but also prediabetes leads to functional decline and disability in older adults. Diabetes Care. 2021;44(3):690-698. doi:10.2337/dc20-2232 33446522
62 Cheval B, Maltagliati S, Sieber S, et al. Why are individuals with diabetes less active? The mediating role of physical, emotional, and cognitive factors. Ann Behav Med. 2021;55(9):904-917. doi:10.1093/abm/kaaa120 33491067
63 Park SW, Goodpaster BH, Strotmeyer ES, et al. Accelerated loss of skeletal muscle strength in older adults with type 2 diabetes: the Health, Aging, and Body Composition Study. Diabetes Care. 2007;30(6):1507-1512. doi:10.2337/dc06-2537 17363749
64 Volpato S, Bianchi L, Lauretani F, et al. Role of muscle mass and muscle quality in the association between diabetes and gait speed. Diabetes Care. 2012;35(8):1672-1679. doi:10.2337/dc11-2202 22596176
65 Lee CG, Schwartz AV, Yaffe K, Hillier TA, LeBlanc ES, Cawthon PM. Changes in physical performance in older women according to presence and treatment of diabetes mellitus. J Am Geriatr Soc. 2013;61(11):1872-1878. doi:10.1111/jgs.12502 24219188
66 Campbell PT, Newton CC, Patel AV, Jacobs EJ, Gapstur SM. Diabetes and cause-specific mortality in a prospective cohort of one million U.S. adults. Diabetes Care. 2012;35(9):1835-1844. doi:10.2337/dc12-0002 22699290
67 Einarson TR, Acs A, Ludwig C, Panton UH. Prevalence of cardiovascular disease in type 2 diabetes: a systematic literature review of scientific evidence from across the world in 2007–2017. Cardiovasc Diabetol. 2018;17(1):83. doi:10.1186/s12933-018-0728-6 29884191
68 Barrett AM, Lucero MA, Le T, Robinson RL, Dworkin RH, Chappell AS. Epidemiology, public health burden, and treatment of diabetic peripheral neuropathic pain: a review. Pain Med. 2007;8(Suppl 2):S50-S62. doi:10.1111/j.1526-4637.2006.00179.x 17714116
69 Armstrong DG, Boulton AJM, Bus SA. Diabetic foot ulcers and their recurrence. N Engl J Med. 2017;376(24):2367-2375. doi:10.1056/NEJMra1615439 28614678
70 Zhang Y, Lazzarini PA, McPhail SM, van Netten JJ, Armstrong DG, Pacella RE. Global disability burdens of diabetes-related lower-extremity complications in 1990 and 2016. Diabetes Care. 2020;43(5):964-974. doi:10.2337/dc19-1614 32139380
71 Leasher JL, Bourne RR, Flaxman SR, et al. Global estimates on the number of people blind or visually impaired by diabetic retinopathy: a meta-analysis from 1990 to 2010. Diabetes Care. 2016;39(9):1643-1649. doi:10.2337/dc15-2171 27555623
72 Willis JR, Doan QV, Gleeson M, et al. Vision-related functional burden of diabetic retinopathy across severity levels in the United States. JAMA Ophthalmol. 2017;135(9):926-932. doi:10.1001/jamaophthalmol.2017.2553 28750122
73 Thomas B. The global burden of diabetic kidney disease: time trends and gender gaps. Curr Diab Rep. 2019;19(4):18. doi:10.1007/s11892-019-1133-6 30826889
74 Zelnick LR, Weiss NS, Kestenbaum BR, et al. Diabetes and CKD in the United States population, 2009–2014. Clin J Am Soc Nephrol. 2017;12(12):1984-1990. doi:10.2215/CJN.03700417 29054846
75 Elshahat S, Cockwell P, Maxwell AP, Griffin M, O’Brien T, O’Neill C. The impact of chronic kidney disease on developed countries from a health economics perspective: a systematic scoping review. PLoS One. 2020;15(3):e0230512. doi:10.1371/journal.pone.0230512 32208435
76 Plantinga LC, Johansen K, Crews DC, et al. Association of CKD with disability in the United States. Am J Kidney Dis. 2011;57(2):212-227. doi:10.1053/j.ajkd.2010.08.016 21036441
77 van Sloten TT, Sedaghat S, Carnethon MR, Launer LJ, Stehouwer CDA. Cerebral microvascular complications of type 2 diabetes: stroke, cognitive dysfunction, and depression. Lancet Diabetes Endocrinol. 2020;8(4):325-336. doi:10.1016/S2213-8587(19)30405-X 32135131
78 Nouwen A, Adriaanse MC, van Dam K, et al. Longitudinal associations between depression and diabetes complications: a systematic review and meta-analysis. Diabet Med. 2019;36(12):1562-1572. doi:10.1111/dme.14054 31215077
79 Smith KJ, Deschênes SS, Schmitz N. Investigating the longitudinal association between diabetes and anxiety: a systematic review and meta-analysis. Diabet Med. 2018;35(6):677-693. doi:10.1111/dme.13606 29460506
80 Sinclair AJ, Abdelhafiz AH, Rodríguez-Mañas L. Frailty and sarcopenia—newly emerging and high impact complications of diabetes. J Diabetes Complications. 2017;31(9):1465-1473. doi:10.1016/j.jdiacomp.2017.05.003 28669464
81 Kalyani RR, Corriere M, Ferrucci L. Age-related and disease-related muscle loss: the effect of diabetes, obesity, and other diseases. Lancet Diabetes Endocrinol. 2014;2(10):819-829. doi:10.1016/S2213-8587(14)70034-8 24731660
82 Qiu S, Cai X, Zhou X, et al. Muscle quality in relation to prediabetes phenotypes: a population-based study with mediation analysis. J Clin Endocrinol Metab. 2024;109(3):e1151-e1158. doi:10.1210/clinem/dgad630 37878955
83 Abdelhafiz AH, Peters S, Sinclair AJ. Low glycaemic state increases risk of frailty and functional decline in older people with type 2 diabetes mellitus. Evidence from a systematic review. Diabetes Res Clin Pract. 2021;181:109085. doi:10.1016/j.diabres.2021.109085 34634389
84 Volpato S, Maraldi C. Diabetes and disability, cognitive decline, and aging-related outcomes. In: Narayan KMV, Williams D, Gregg EW, Cowie CC, eds. Diabetes Public Health: From Data to Policy. Oxford University Press;2010:225–246:chap 11.
85 Bardenheier BH, Gregg EW, Zhuo X, Cheng YJ, Geiss LS. Association of functional decline with subsequent diabetes incidence in U.S. adults aged 51 years and older: the Health and Retirement Study 1998–2010. Diabetes Care. 2014;37(4):1032-1038. doi:10.2337/dc13-2216 24550218
86 Gordon PS, Farkas GJ, Gater DR, Jr. Neurogenic obesity-induced insulin resistance and type 2 diabetes mellitus in chronic spinal cord injury. Top Spinal Cord Inj Rehabil. 2021;27(1):36-56. doi:10.46292/sci20-00063 33814882
87 Kendzerska T, King LK, Lipscombe L, Croxford R, Stanaitis I, Hawker GA. The impact of hip and knee osteoarthritis on the subsequent risk of incident diabetes: a population-based cohort study. Diabetologia. 2018;61(11):2290-2299. doi:10.1007/s00125-018-4703-2 30091045
88 Felson DT, Zhang Y, Anthony JM, Naimark A, Anderson JJ. Weight loss reduces the risk for symptomatic knee osteoarthritis in women. The Framingham Study. Ann Intern Med. 1992;116(7):535-539. doi:10.7326/0003-4819-116-7-535 1543306
89 Messier SP, Loeser RF, Miller GD, et al. Exercise and dietary weight loss in overweight and obese older adults with knee osteoarthritis: the Arthritis, Diet, and Activity Promotion Trial. Arthritis Rheum. 2004;50(5):1501-1510. doi:10.1002/art.20256 15146420
90 Villareal DT, Chode S, Parimi N, et al. Weight loss, exercise, or both and physical function in obese older adults. N Engl J Med. 2011;364(13):1218-1229. doi:10.1056/NEJMoa1008234 21449785
91 Rejeski WJ, Brubaker PH, Goff DC, Jr., et al. Translating weight loss and physical activity programs into the community to preserve mobility in older, obese adults in poor cardiovascular health. Arch Intern Med. 2011;171(10):880-886. doi:10.1001/archinternmed.2010.522 21263080
92 Rejeski WJ, Ip EH, Bertoni AG, et al. Lifestyle change and mobility in obese adults with type 2 diabetes. N Engl J Med. 2012;366(13):1209-1217. doi:10.1056/NEJMoa1110294 22455415
93 Gregg EW, Lin J, Bardenheier B, et al. Impact of intensive lifestyle intervention on disability-free life expectancy: the Look AHEAD study. Diabetes Care. 2018;41(5):1040-1048. doi:10.2337/dc17-2110 29545462
94 Houston DK, Leng X, Bray GA, et al. A long-term intensive lifestyle intervention and physical function: the Look AHEAD Movement and Memory Study. Obesity (Silver Spring). 2015;23(1):77-84. doi:10.1002/oby.20944 25452229
95 Houston DK, Neiberg RH, Miller ME, et al. Physical function following a long-term lifestyle intervention among middle aged and older adults with type 2 diabetes: the Look AHEAD study. J Gerontol A Biol Sci Med Sci. 2018;73(11):1552-1559. doi:10.1093/gerona/glx204 29053861
96 Morikawa M, Lee S, Makino K, et al. Social isolation and risk of disability in older adults: effect modification of metabolic syndrome. Arch Gerontol Geriatr. 2024;116:105209. doi:10.1016/j.archger.2023.105209 37782966
97 Tsai YH, Chuang LL, Lee YJ, Chiu CJ. Behavioral and psychological factors in buffering diabetes-related disability development. Ann Behav Med. 2023;57(12):1046-1057. doi:10.1093/abm/kaad038 37549141
98 Shang Y, Wu W, Dove A, et al. Healthy behaviors, leisure activities, and social network prolong disability-free survival in older adults with diabetes. J Gerontol A Biol Sci Med Sci. 2022;77(10):2093-2101. doi:10.1093/gerona/glac054 35239961
99 McCaffery JM, Anderson A, Coday M, et al. Loneliness relates to functional mobility in older adults with type 2 diabetes: the Look AHEAD study. J Aging Res. 2020;2020:7543702. doi:10.1155/2020/7543702 33178459
100 Oyewole OO, Ale AO, Ogunlana MO, Gurayah T. Burden of disability in type 2 diabetes mellitus and the moderating effects of physical activity. World J Clin Cases. 2023;11(14):3128-3139. doi:10.12998/wjcc.v11.i14.3128 37274052
101 Buss SS, Aponte Becerra L, Trevino J, Fortier CB, Ngo LH, Novak V. Depressive symptoms exacerbate disability in older adults: a prospective cohort analysis of participants in the MemAID trial. PLoS One. 2022;17(11):e0278319. doi:10.1371/journal.pone.0278319 36445876
102 Diabetes Prevention Program Research Group. Long-term effects of lifestyle intervention or metformin on diabetes development and microvascular complications over 15-year follow-up: the Diabetes Prevention Program Outcomes Study. Lancet Diabetes Endocrinol. 2015;3(11):866-875. doi:10.1016/S2213-8587(15)00291-0 26377054
103 Gong Q, Zhang P, Wang J, et al. Morbidity and mortality after lifestyle intervention for people with impaired glucose tolerance: 30-year results of the Da Qing Diabetes Prevention Outcome Study. Lancet Diabetes Endocrinol. 2019;7(6):452-461. doi:10.1016/S2213-8587(19)30093-2 31036503
104 Bandosz P, Ahmadi-Abhari S, Guzman-Castillo M, et al. Potential impact of diabetes prevention on mortality and future burden of dementia and disability: a modelling study. Diabetologia. 2020;63(1):104-115. doi:10.1007/s00125-019-05015-4 31732789
105 American Diabetes Association. 9. Pharmacologic Approaches to Glycemic Treatment: Standards of Care in Diabetes-2024. Diabetes Care. 2024;47(Suppl 1):S158-S178. doi:10.2337/dc24-S009 38078590
106 Kosiborod MN, Petrie MC, Borlaug BA, et al. Semaglutide in patients with obesity-related heart failure and type 2 diabetes. N Engl J Med. 2024;390(15):1394-1407. doi:10.1056/NEJMoa2313917 38587233
107 American Diabetes Association Professional Practice Committee. 4. Comprehensive Medical Evaluation and Assessment of Comorbidities: Standards of Care in Diabetes-2024. Diabetes Care. 2024;47(Suppl 1):S52-S76. doi:10.2337/dc24-S004 38078591

FIGURE 1.

The International Classification of Functioning, Disability and Health Model of Disability.

SOURCE: Adapted from reference (26).

Model graphic showing that contextual factors interact with health conditions, including diabetes, that may lead to body impairments and, in turn, disability.

FIGURE 2.

Age-Standardized Prevalence of Disability Among Adults Age ≥20 Years, by Glycemic Status, U.S., 2015–2018.

Diagnosed diabetes and disability status are based on self-report. Undiagnosed diabetes is defined as A1C ≥6.5% or FPG ≥126 mg/dL and no self-report of diabetes. Prediabetes is defined as A1C 5.7%–<6.5% or FPG 100–125 mg/dL. Normal glucose levels are defined as A1C <5.7% and FPG <100 mg/dL. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. Error bars represent 95% confidence intervals. Conversion formulas for A1C and glucose values are provided in the Conversions section. A1C, glycated hemoglobin; ADL, activities of daily living; FPG, fasting plasma glucose; IADL, instrumental activities of daily living.

* Any disability is defined as having vision disability, hearing disability, mobility disability, IADL disability, or ADL disability; any disability does not include work disability.

† Vision disability is defined as being blind or have serious difficulty seeing even when wearing glasses.

‡ Hearing disability is defined as being deaf or have serious difficulty hearing.

§ Mobility disability is defined as self-reporting needing special equipment to walk or have much difficulty/unable/do not: (1.) walk a quarter mile, (2.) walk up 10 steps, (3.) stoop/crouch/kneel, (4.) walk between rooms, (5.) stand up from armless chair, or (6.) get in/out of bed.

║ IADL disability is defined as self-reporting unable/do not do: (1.) household chores or (2.) prepare meals.

¶ ADL disability is defined as self-reporting unable/do not: (1.) use fork/knife/drink or (2.) dress oneself.

# Work disability is defined as self-reporting limitations keeping you from working. Work disability is not included in the “any disability” category.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2015–2018

Bar graph showing that adults with diagnosed diabetes had a higher prevalence of any disability, and individual disability components, compared to those with undiagnosed diabetes, prediabetes, or normal glucose.

FIGURE 3.

Age-Standardized Trends in Prevalence of Disability Among Adults Age ≥20 Years With Diagnosed Diabetes, U.S., NHANES 2015–2018 and NHIS 2019–2022.

Diabetes is self-reported. Any disability in the NHANES 2015–2018 includes vision disability, hearing disability, mobility disability, IADL disability, and ADL disability. Any disability in the NHIS 2019–2022 is defined using the Washington Group Short Set Composite Disability Indicators, which include vision disability, hearing disability, mobility disability, communication disability, cognitive disability, and self-care disability. Data are age-standardized to the NHIS 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. ADL, activities of daily living; IADL, instrumental activities of daily living.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2015–2018 and National Health Interview Surveys (NHIS) 2019–2022

Line graph showing that trends in the prevalence of disability among adults with diabetes have been stable between 2015 and 2022.

FIGURE 4.

Age-Standardized Prevalence of Disability Among Adults With Diagnosed Diabetes, by Race and Ethnicity, U.S., 2019–2022.

Diabetes is self-reported. Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have a disability. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. Error bars represent 95% confidence intervals.

^1^ Relative standard error >30%–40%

SOURCE: National Health Interview Surveys 2019–2022

Bar graph showing that non-Hispanic White adults with diabetes had a higher prevalence of any disability compared to non-Hispanic Black, Hispanic, and non-Hispanic Asian persons.

FIGURE 5.

Age-Standardized Prevalence of Disability Among Adults With Diagnosed Diabetes, by Education, U.S., 2019–2022.

Diabetes is self-reported. Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have a disability. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. Error bars represent 95% confidence intervals. GED, general equivalency diploma.

SOURCE: National Health Interview Surveys 2019–2022

Bar graph showing that, among adults with diabetes, those with less than a high school education had a higher prevalence of any disability compared to their counterparts with greater than a high school education.

FIGURE 6.

Age-Standardized Prevalence of Disability Among Adults With Diagnosed Diabetes, by Poverty Income Ratio, U.S., 2019–2022.

Diabetes is self-reported. Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have a disability. The poverty income ratio (PIR) is defined as family income divided by the federal poverty threshold. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. Error bars represent 95% confidence intervals.

SOURCE: National Health Interview Surveys 2019–2022

Bar graph showing that, among adults with diabetes, those with a poverty income ratio below the poverty threshold had a higher prevalence of any disability, and most individual disability components, compared to those with a poverty income ratio above the poverty threshold.

FIGURE 7.

Age-Standardized Prevalence of Disability Among Adults With Diagnosed Diabetes, by Health Insurance Status, U.S., 2019–2022.

Diabetes and health insurance status are self-reported. Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have a disability. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. Error bars represent 95% confidence intervals.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

SOURCE: National Health Interview Surveys 2019–2022

Bar graph showing that, among adults with diabetes, those with Medicare or Medicaid had a higher prevalence of any disability and mobility disability compared to those with private insurance or no insurance.

TABLE 1.

Age-Standardized Prevalence of Disability Among Adults Age ≥20 Years With Diagnosed Diabetes, by Demographic, Socioeconomic, and Health Factors, U.S., 2015–2018

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Any Disability* | Vision Disability^†^ | Hearing Disability^‡^ | Mobility Disability^§^ | IADL Disability^║^ | ADL Disability^¶^ | Work Disability^#^
Total | 40.1 (2.5) | 13.2 (1.6) | 13.3 (1.2) | 27.6 (2.3) | 6.0 (0.9) | 1.0 (0.2) | 24.7 (2.4)
Age (years)
20–44 | 28.7 (4.5) | 13.8 (3.4) | 8.5 (1.9) | 15.2 (3.7) | ^3^ | ^3^ | 21.6 (4.8)
45–64 | 37.4 (2.4) | 11.3 (1.9) | 10.3 (1.6) | 28.2 (2.5) | 4.2 (0.8) | 1.7 (0.7)^1^ | 27.3 (2.0)
65–74 | 56.7 (3.5) | 13.8 (2.2) | 20.3 (2.7) | 39.8 (3.6) | 9.7 (1.8) | 1.0 (0.4)^2^ | 25.8 (2.7)
≥75 | 82.8 (2.8) | 16.5 (2.7) | 38.5 (3.4) | 69.3 (3.3) | 25.4 (2.6) | 2.9 (1.2)^2^ | 28.7 (2.2)
Sex
Men | 36.3 (3.2) | 10.0 (1.7) | 16.3 (2.2) | 24.3 (3.4) | 6.7 (1.6) | 0.9 (0.3)^1^ | 22.3 (3.4)
Women | 43.9 (3.5) | 16.2 (2.5) | 10.1 (1.2) | 31.8 (2.7) | 5.5 (0.7) | 1.0 (0.3) | 27.2 (2.7)
Race and ethnicity
Non-Hispanic White | 42.4 (3.8) | 13.9 (3.1) | 12.8 (1.9) | 28.7 (3.6) | 5.6 (1.6) | 0.7 (0.2) | 25.9 (3.8)
Non-Hispanic Black | 35.0 (3.4) | 9.3 (1.6) | 8.4 (2.2) | 27.3 (2.7) | 5.1 (1.5)^1^ | ^3^ | 26.0 (3.1)
All Hispanic | 40.9 (2.3) | 17.4 (2.5) | 16.6 (1.8) | 27.5 (2.3) | 8.6 (1.4) | 1.4 (0.5)^1^ | 23.6 (2.5)
Non-Hispanic Asian | 22.8 (2.9) | 4.5 (1.2) | 3.8 (0.8) | 17.8 (2.0) | 8.3 (2.1) | ^3^ | 9.5 (1.4)
Education
<9th grade | 57.7 (6.1) | 25.3 (5.0) | 19.7 (4.4) | 42.9 (6.1) | 19.2 (5.9)^1^ | 1.9 (0.8)^2^ | 39.2 (6.7)
9th–11th grade | 52.5 (7.0) | 19.0 (4.5) | 16.6 (3.4) | 41.6 (7.4) | 9.0 (1.6) | ^3^ | 41.3 (7.5)
High school graduate | 41.4 (3.8) | 12.4 (2.4) | 14.6 (3.1) | 30.9 (3.5) | 4.5 (0.8) | 0.9 (0.3)^1^ | 29.2 (4.6)
Some college | 39.0 (3.4) | 10.8 (2.9) | 12.9 (2.0) | 25.7 (2.3) | 4.6 (0.9) | 0.8 (0.3)^1^ | 22.4 (3.0)
College graduate | 26.8 (6.8) | ^3^ | 8.2 (2.2) | 13.2 (1.9) | 3.0 (0.8) | ^3^ | 8.0 (1.7)
Health insurance
Any | 39.3 (3.1) | 13.7 (2.0) | 11.5 (1.1) | 27.8 (2.5) | 5.5 (0.6) | 1.0 (0.2) | 25.1 (2.6)
No insurance | 45.9 (4.0) | 13.5 (3.1) | 24.1 (4.2) | 31.1 (3.9) | 7.9 (3.6)^2^ | ^3^ | 20.3 (4.1)
Private | 29.6 (2.9) | 9.1 (2.5) | 9.1 (1.2) | 18.5 (2.1) | 3.5 (0.5) | 0.3 (0.2)^2^ | 11.6 (1.6)
Medicare, age ≥65 years | 67.4 (2.6) | 14.0 (1.7) | 27.6 (2.2) | 52.4 (2.5) | 15.8 (1.6) | 1.9 (0.6)^1^ | 28.2 (1.9)
Medicaid | 62.7 (5.8) | 26.9 (4.7) | 18.6 (4.4) | 54.1 (6.0) | 13.5 (2.4) | 1.9 (0.7)^1^ | 55.3 (4.8)
Duration of diabetes (years)**
<2 | 36.8 (5.2) | 7.5 (2.7)^1^ | 11.5 (3.3) | 29.0 (5.6) | 10.7 (3.7)^1^ | ^3^ | 24.3 (5.8)
2–5 | 46.7 (5.1) | 17.2 (4.9) | 11.0 (2.4) | 29.8 (4.4) | 4.5 (1.4)^1^ | ^3^ | 30.0 (3.3)
6–15 | 35.0 (3.2) | 11.0 (3.0) | 11.5 (1.9) | 24.0 (2.7) | 4.7 (0.8) | 1.0 (0.3)^1^ | 22.3 (3.6)
>15 | 40.4 (4.0) | 16.5 (3.1) | 16.6 (2.7) | 27.9 (3.5) | 5.8 (0.7) | 0.6 (0.2)^1^ | 24.6 (4.2)
Body mass index (kg/m^2^)^††^
<25.0 | 34.2 (7.6) | 11.7 (4.1)^1^ | 12.6 (5.0)^2^ | 25.4 (7.8)^1^ | ^3^ | ^3^ | 23.2 (7.7)^1^
25.0–<30.0 | 27.7 (3.2) | 11.0 (2.6) | 9.9 (1.9) | 15.1 (1.8) | 4.4 (0.6) | ^3^ | 14.6 (2.3)
30.0–<35.0 | 33.5 (4.6) | 12.2 (3.5) | 10.8 (1.6) | 20.5 (2.3) | 3.7 (1.0) | ^3^ | 22.5 (4.3)
≥35.0 | 50.9 (3.6) | 12.9 (2.3) | 17.8 (2.6) | 40.3 (3.3) | 5.7 (0.8) | 0.9 (0.3)^1^ | 30.6 (2.7)
Current smoker**
Yes | 49.8 (6.8) | 15.6 (4.0) | 14.3 (3.0) | 40.6 (5.9) | 10.3 (3.2)^1^ | 1.0 (0.4)^2^ | 39.2 (5.0)
No | 45.9 (4.3) | 17.6 (4.6) | 16.4 (2.6) | 27.6 (3.4) | 4.2 (0.6) | ^3^ | 28.5 (4.6)
Coronary heart disease**
Yes | 60.5 (11.7) | ^3^ | 12.3 (2.7) | 42.5 (14.3)^1^ | 6.4 (1.4) | ^3^ | 41.7 (12.5)^1^
No | 39.0 (2.5) | 13.2 (1.6) | 12.8 (1.3) | 26.7 (2.4) | 5.7 (0.9) | 1.1 (0.2) | 23.9 (2.4)
Heart failure**
Yes | 47.6 (9.5) | 20.9 (8.2)^1^ | 28.2 (9.2)^1^ | 43.1 (9.9) | 15.0 (3.0) | 4.0 (1.4)^1^ | 47.0 (11.2)
No | 38.9 (2.4) | 12.4 (1.6) | 12.2 (1.2) | 26.2 (2.3) | 5.0 (0.9) | 0.7 (0.2) | 22.9 (2.4)
Cancer**
Yes | 57.9 (7.5) | 28.8 (10.3)^1^ | 17.7 (6.7)^1^ | 34.6 (8.1) | 4.6 (0.9) | 1.3 (0.5)^2^ | 46.6 (8.0)
No | 39.0 (2.3) | 12.3 (1.4) | 12.9 (1.3) | 26.9 (2.2) | 6.0 (0.9) | 0.7 (0.2) | 23.4 (2.2)
Arthritis**
Yes | 58.5 (4.8) | 15.1 (3.3) | 15.3 (2.2) | 48.4 (4.8) | 9.5 (2.6) | 1.5 (0.5)^1^ | 46.5 (5.3)
No | 29.5 (2.1) | 11.7 (1.8) | 12.4 (1.5) | 14.4 (1.3) | 3.9 (0.5) | 0.6 (0.3)^2^ | 12.6 (1.5)
Stroke**
Yes | 72.2 (7.4) | 18.2 (5.9)^1^ | 36.0 (10.9)^1^ | 56.1 (8.0) | 11.4 (1.8) | ^3^ | 70.0 (7.1)
No | 37.3 (2.4) | 12.4 (1.7) | 12.1 (1.1) | 25.0 (2.0) | 5.3 (0.9) | 0.7 (0.2) | 21.7 (2.2)
Chronic kidney disease^‡‡^
Yes | 48.7 (10.3) | 10.2 (1.4) | 9.9 (1.1) | 43.6 (10.6) | ^3^ | 3.0 (1.2)^1^ | 40.3 (10.1)
No | 37.8 (2.4) | 11.6 (1.5) | 13.6 (1.4) | 26.3 (2.5) | 5.3 (1.0) | 0.8 (0.3)^1^ | 23.1 (2.6)
End-stage kidney disease^‡‡^
Yes | 88.8 (6.1) | 13.6 (4.9)^1^ | 16.7 (6.6)^1^ | 85.0 (6.8) | 57.1 (6.7) | ^3^ | 82.7 (5.0)
No | 38.8 (2.4) | 12.0 (1.4) | 13.4 (1.2) | 27.5 (2.5) | 5.6 (0.9) | 1.0 (0.2) | 24.5 (2.5)
Vision problems**
Yes | 100 | 100 | 27.2 (5.1) | 46.9 (7.1) | 9.2 (1.3) | 1.7 (0.7)^1^ | 48.8 (7.7)
No | 31.1 (1.9) | NA | 11.2 (1.2) | 24.8 (2.0) | 5.6 (1.0) | 0.9 (0.2) | 21.1 (2.1)
Depression^§§^
Yes | 82.0 (4.0) | 32.1 (4.7) | 31.4 (5.1) | 62.8 (6.4) | 16.0 (5.7)^1^ | ^3^ | 57.8 (6.4)
No | 33.5 (2.3) | 10.0 (1.5) | 11.1 (1.3) | 22.4 (2.1) | 3.8 (0.5) | 0.9 (0.2) | 19.9 (2.4)
Self-reported health**
Excellent/very good | 16.6 (3.3) | 3.2 (1.4)^2^ | 8.1 (2.4) | 9.5 (1.7) | 2.1 (0.8)^1^ | ^3^ | 6.7 (1.9)
Good | 31.3 (4.1) | 10.1 (3.7)^1^ | 9.1 (1.2) | 19.0 (2.2) | 3.4 (0.5) | 0.6 (0.2)^1^ | 18.2 (3.4)
Fair/poor | 60.6 (3.4) | 21.6 (2.1) | 21.4 (2.5) | 46.1 (4.0) | 10.2 (2.2) | 1.7 (0.6)^1^ | 40.8 (3.9)
COPD/chronic lung disease**
Yes | 69.8 (6.4) | 21.7 (7.8)^1^ | 21.9 (3.2) | 53.2 (8.9) | 8.7 (2.2) | 0.9 (0.4)^2^ | 47.6 (9.4)
No | 35.9 (2.0) | 12.0 (1.5) | 11.6 (1.2) | 23.3 (1.9) | 5.5 (0.9) | 1.0 (0.3) | 21.0 (1.9)

Diabetes and disability statuses are self-reported. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. ADL, activities of daily living; COPD, chronic obstructive pulmonary disease; eGFR, estimated glomerular filtration rate; IADL, instrumental activities of daily living; NA, not applicable.

* Any disability includes vision disability, hearing disability, mobility disability, IADL disability, and ADL disability; any disability does not include work disability.

† Vision disability is defined as being blind or have serious difficulty seeing even when wearing glasses.

‡ Hearing disability is defined as being deaf or have serious difficulty hearing.

§ Mobility disability is defined as self-reporting needing special equipment to walk or have much difficulty/unable/do not: (1.) walk a quarter mile, (2.) walk up 10 steps, (3.) stoop/crouch/kneel, (4.) walk between rooms, (5.) stand up from armless chair, or (6.) get in/out of bed.

║ IADL disability is defined as self-reporting unable/do not do: (1.) household chores or (2.) prepare meals.

¶ ADL disability is defined as self-reporting unable/do not: (1.) use fork/knife/drink or (2.) dress oneself.

# Work disability is defined as self-reporting limitations keeping you from working. Work disability is not included in the “any disability” category.

** Self-reported data

†† Body mass index is based on measured height and weight.

‡‡ Chronic kidney disease is based on eGFR <60 mL/min/1.73 m^2^; end-stage kidney disease is based on eGFR <15 mL/min/1.73 m^2^.

§§ Patient Health Questionnaire-9 (PHQ-9) ≥10

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 2015–2018

TABLE 2.

Prevalence of Disability and Some Functional Difficulty Among Women Age ≥20 Years, by Diabetes Status and Age, U.S., 2019–2022

DISABILITY DOMAIN | PERCENT (STANDARD ERROR)
DISABILITY DOMAIN | Diabetes | | | | | | No Diabetes
DISABILITY DOMAIN | | | Age (Years) | | | | | | Age (Years)
DISABILITY DOMAIN | Unadjusted | Age-standardized* | 20–44 | 45–64 | 65–74 | ≥75 | Unadjusted | Age-standardized* | 20–44 | 45–64 | 65–74 | ≥75
Any Disability^†^ | 26.2 (0.7) | 21.0 (0.9) | 13.8 (1.9) | 23.3 (1.0) | 26.3 (1.2) | 39.3 (1.6) | 8.4 (0.2) | 8.5 (0.2) | 4.2 (0.2) | 8.5 (0.3) | 11.3 (0.4) | 24.8 (0.6)
Vision
Disability^‡^ | 4.6 (0.3) | 4.4 (0.7) | 4.3 (1.4)^1^ | 4.2 (0.5) | 3.9 (0.5) | 6.9 (0.8) | 1.5 (0.1) | 1.5 (0.1) | 0.7 (0.1) | 1.7 (0.1) | 1.9 (0.2) | 3.8 (0.3)
Some difficulty^§^ | 26.4 (0.7) | 24.6 (1.0) | 20.2 (2.0) | 29.9 (1.2) | 25.1 (1.1) | 25.0 (1.4) | 16.3 (0.2) | 16.5 (0.2) | 12.8 (0.3) | 19.7 (0.4) | 17.7 (0.5) | 20.4 (0.6)
Hearing
Disability | 3.1 (0.3) | 2.3 (0.3) | 1.6 (0.6)^1^ | 2.1 (0.4) | 2.8 (0.5) | 6.5 (0.9) | 1.2 (0.1) | 1.2 (0.1) | 0.6 (0.1) | 1.0 (0.1) | 1.2 (0.1) | 4.6 (0.3)
Some difficulty | 19.1 (0.6) | 14.6 (0.7) | 8.4 (1.4) | 16.6 (0.9) | 20.8 (1.1) | 28.4 (1.4) | 11.0 (0.2) | 11.1 (0.2) | 6.0 (0.2) | 10.7 (0.3) | 16.6 (0.5) | 29.8 (0.7)
Mobility
Disability | 20.1 (0.6) | 14.8 (0.8) | 7.7 (1.6) | 17.0 (0.9) | 22.2 (1.1) | 30.8 (1.4) | 4.9 (0.1) | 5.0 (0.1) | 1.1 (0.1) | 5.3 (0.2) | 8.4 (0.4) | 18.5 (0.6)
Some difficulty | 30.8 (0.7) | 24.4 (0.9) | 14.7 (1.7) | 29.7 (1.2) | 35.1 (1.4) | 36.9 (1.5) | 13.5 (0.2) | 13.8 (0.2) | 5.7 (0.2) | 15.2 (0.3) | 23.4 (0.5) | 33.8 (0.6)
Communication
Disability | 1.4 (0.2) | 1.0 (0.2) | ^2^ | 1.0 (0.2) | 1.3 (0.4) | 3.1 (0.6) | 0.7 (0.0) | 0.7 (0.0) | 0.5 (0.1) | 0.4 (0.1) | 0.7 (0.1) | 2.4 (0.3)
Some difficulty | 7.4 (0.4) | 7.4 (0.6) | 7.4 (1.2) | 7.3 (0.7) | 5.5 (0.6) | 10.4 (1.0) | 3.7 (0.1) | 3.7 (0.1) | 3.1 (0.2) | 3.1 (0.2) | 3.7 (0.2) | 8.1 (0.4)
Cognitive
Disability | 5.3 (0.4) | 5.5 (0.6) | 5.9 (1.2) | 5.2 (0.6) | 3.6 (0.5) | 7.7 (1.0) | 2.4 (0.1) | 2.4 (0.1) | 2.3 (0.1) | 1.9 (0.1) | 1.4 (0.2) | 5.7 (0.4)
Some difficulty | 29.3 (0.7) | 26.4 (1.1) | 22.5 (2.2) | 27.7 (1.2) | 30.1 (1.2) | 35.3 (1.5) | 16.7 (0.2) | 16.8 (0.2) | 13.4 (0.3) | 15.7 (0.3) | 19.7 (0.5) | 32.9 (0.7)
Self-Care
Disability | 4.0 (0.3) | 3.0 (0.6) | ^2^ | 2.3 (0.3) | 3.1 (0.5) | 9.5 (1.2) | 0.9 (0.1) | 0.9 (0.1) | 0.4 (0.1) | 0.5 (0.1) | 1.0 (0.2) | 4.7 (0.3)
Some difficulty | 8.6 (0.4) | 6.9 (0.5) | 4.2 (0.9) | 8.6 (0.7) | 8.9 (0.8) | 10.9 (1.0) | 2.7 (0.1) | 2.7 (0.1) | 1.5 (0.1) | 2.7 (0.1) | 3.0 (0.2) | 8.5 (0.4)

Diabetes status is self-reported.

* Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years.

† Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have any disability.

‡ Disability is defined for adults who responded “a lot of difficulty” or “cannot do at all.”

§ Some functional difficulty is defined for adults who responded having “some difficulty.”

^1^ Relative standard error >30%–40%

^2^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2019–2022

TABLE 3.

Prevalence of Disability and Some Functional Difficulty Among Men Age ≥20 Years, by Diabetes Status and Age, U.S., 2019–2022

DISABILITY DOMAIN | PERCENT (STANDARD ERROR)
DISABILITY DOMAIN | Diabetes | | | | | | No Diabetes
DISABILITY DOMAIN | | | Age (Years) | | | | | | Age (Years)
DISABILITY DOMAIN | Unadjusted | Age-standardized* | 20–44 | 45–64 | 65–74 | ≥75 | Unadjusted | Age-standardized* | 20–44 | 45–64 | 65–74 | ≥75
Any Disability^†^ | 21.6 (0.6) | 18.8 (1.0) | 15.6 (2.1) | 17.4 (1.0) | 22.4 (1.2) | 34.3 (1.5) | 6.6 (0.1) | 7.1 (0.1) | 3.4 (0.2) | 6.7 (0.3) | 10.6 (0.4) | 21.9 (0.7)
Vision
Disability^‡^ | 3.8 (0.3) | 3.0 (0.3) | 1.7 (0.6)^1^ | 4.0 (0.5) | 2.9 (0.5) | 6.0 (0.7) | 1.0 (0.1) | 1.1 (0.1) | 0.5 (0.1) | 1.1 (0.1) | 1.5 (0.2) | 3.2 (0.3)
Some difficulty^§^ | 22.6 (0.6) | 20.7 (1.0) | 17.3 (2.2) | 24.0 (1.0) | 22.5 (1.2) | 22.7 (1.4) | 13.1 (0.2) | 13.6 (0.2) | 8.7 (0.3) | 17.6 (0.4) | 16.3 (0.5) | 18.4 (0.7)
Hearing
Disability | 4.6 (0.3) | 3.5 (0.4) | 2.0 (0.8)^1^ | 3.3 (0.5) | 4.9 (0.6) | 9.2 (1.0) | 1.5 (0.1) | 1.7 (0.1) | 0.5 (0.1) | 1.5 (0.1) | 2.7 (0.2) | 6.7 (0.4)
Some difficulty | 23.1 (0.6) | 17.3 (0.8) | 9.8 (1.7) | 17.3 (0.9) | 29.3 (1.2) | 36.2 (1.5) | 14.1 (0.2) | 15.1 (0.2) | 7.2 (0.2) | 15.2 (0.4) | 26.1 (0.6) | 37.3 (0.8)
Mobility
Disability | 14.8 (0.5) | 11.8 (0.8) | 8.1 (1.6) | 11.7 (0.8) | 16.0 (1.0) | 24.7 (1.4) | 3.2 (0.1) | 3.6 (0.1) | 0.9 (0.1) | 3.5 (0.2) | 6.6 (0.4) | 12.5 (0.5)
Some difficulty | 24.4 (0.7) | 19.7 (0.9) | 12.8 (1.8) | 22.5 (1.0) | 28.0 (1.3) | 30.5 (1.5) | 9.7 (0.2) | 10.6 (0.2) | 4.1 (0.2) | 11.3 (0.3) | 17.4 (0.5) | 29.3 (0.8)
Communication
Disability | 1.7 (0.2) | 1.8 (0.5) | 2.3 (1.0)^2^ | 0.6 (0.2) | 1.8 (0.4) | 3.8 (0.7) | 0.8 (0.1) | 0.8 (0.1) | 0.6 (0.1) | 0.7 (0.1) | 0.8 (0.1) | 2.4 (0.3)
Some difficulty | 7.5 (0.4) | 6.9 (0.6) | 6.3 (1.3) | 6.6 (0.6) | 6.3 (0.7) | 12.0 (1.1) | 4.1 (0.1) | 4.3 (0.1) | 3.4 (0.2) | 3.7 (0.2) | 5.0 (0.3) | 10.1 (0.5)
Cognitive
Disability | 4.6 (0.4) | 4.2 (0.5) | 3.7 (1.1) | 4.2 (0.5) | 3.3 (0.5) | 7.8 (0.9) | 1.9 (0.1) | 2.0 (0.1) | 1.6 (0.1) | 1.7 (0.1) | 1.6 (0.2) | 5.4 (0.4)
Some difficulty | 22.7 (0.7) | 19.6 (0.9) | 15.6 (1.9) | 20.0 (1.0) | 23.6 (1.2) | 31.9 (1.5) | 13.5 (0.2) | 14.1 (0.2) | 11.4 (0.3) | 11.4 (0.3) | 18.3 (0.6) | 30.9 (0.8)
Self-Care
Disability | 3.1 (0.3) | 2.6 (0.4) | 2.3 (0.8)^1^ | 1.6 (0.3) | 3.3 (0.5) | 7.2 (1.0) | 0.7 (0.0) | 0.8 (0.1) | 0.4 (0.1) | 0.5 (0.1) | 1.2 (0.2) | 3.0 (0.3)
Some difficulty | 7.0 (0.4) | 6.8 (0.7) | 6.7 (1.6) | 6.5 (0.6) | 5.7 (0.7) | 10.2 (0.9) | 2.4 (0.1) | 2.5 (0.1) | 1.4 (0.1) | 2.5 (0.2) | 3.3 (0.3) | 7.1 (0.4)

Diabetes status is self-reported.

* Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years.

† Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have any disability.

‡ Disability is defined for adults who responded “a lot of difficulty” or “cannot do at all.”

§ Some functional difficulty is defined for adults who responded having “some difficulty.”

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

SOURCE: National Health Interview Surveys 2019–2022

TABLE 4.

Age-Standardized Prevalence of Disability Among Adults Age ≥20 Years With Diagnosed Diabetes, by Sociodemographic and Health Factors, U.S., 2019–2022

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Any Disability* | Vision Disability | Hearing Disability | Mobility Disability | Communication Disability | Cognitive Disability | Self-Care Disability
Total | 19.9 (0.7) | 3.7 (0.4) | 2.9 (0.3) | 13.3 (0.5) | 1.4 (0.2) | 5.0 (0.4) | 2.8 (0.3)
Age (years)
20–44 | 14.9 (1.5) | 3.0 (0.8) | 1.8 (0.5) | 7.8 (1.1) | 1.4 (0.5) | 5.1 (0.8) | 2.2 (0.7)
45–64 | 20.2 (0.7) | 4.1 (0.3) | 2.7 (0.3) | 14.2 (0.6) | 0.8 (0.1) | 4.6 (0.4) | 1.9 (0.2)
65–74 | 24.4 (0.8) | 3.4 (0.4) | 3.8 (0.4) | 19.1 (0.7) | 1.6 (0.3) | 3.5 (0.4) | 3.2 (0.4)
≥75 | 36.7 (1.1) | 6.4 (0.5) | 7.9 (0.7) | 27.8 (1.0) | 3.6 (0.5) | 7.7 (0.7) | 8.3 (0.8)
Sex
Men | 18.8 (1.0) | 3.0 (0.3) | 3.5 (0.4) | 11.8 (0.8) | 1.8 (0.5) | 4.2 (0.5) | 2.6 (0.4)
Women | 20.9 (0.9) | 4.4 (0.7) | 2.4 (0.3) | 14.8 (0.8) | 1.0 (0.2) | 5.5 (0.6) | 3.0 (0.6)
Race and ethnicity
Non-Hispanic White | 22.5 (1.1) | 3.8 (0.7) | 3.7 (0.5) | 15.4 (0.9) | 1.3 (0.4)^1^ | 5.9 (0.7) | 2.6 (0.6)
Non-Hispanic Black | 18.2 (1.3) | 4.6 (0.7) | 1.8 (0.4) | 11.8 (0.8) | 1.5 (0.5)^1^ | 3.6 (0.9) | 2.5 (0.5)
Hispanic | 18.0 (1.2) | 3.1 (0.5) | 2.1 (0.4) | 11.3 (0.9) | 1.7 (0.6)^1^ | 5.4 (0.8) | 4.2 (0.7)
Non-Hispanic Asian | 12.4 (3.3) | 1.5 (0.6) | 1.4 (0.4) | 8.6 (3.2)^1^ | 1.0 (0.4)^1^ | 2.6 (0.7) | 3.5 (1.3)^1^
Education
<High school | 27.1 (2.1) | 5.3 (1.0) | 3.3 (0.5) | 18.4 (1.8) | 2.7 (0.9) | 7.1 (1.2) | 4.0 (0.9)
High school/GED | 22.4 (1.4) | 4.1 (0.9) | 2.9 (0.3) | 14.5 (1.1) | 2.0 (0.6) | 5.5 (0.9) | 3.3 (0.9)
>High school | 15.8 (0.8) | 2.9 (0.4) | 2.6 (0.4) | 10.6 (0.6) | 0.5 (0.1) | 3.7 (0.5) | 2.0 (0.2)
Poverty income ratio^†^
<1.0 | 34.0 (1.9) | 8.9 (1.5) | 3.3 (0.5) | 25.2 (1.8) | 1.6 (0.3) | 8.7 (0.9) | 5.9 (1.3)
≥1.0 | 17.1 (0.7) | 2.6 (0.3) | 2.9 (0.3) | 10.9 (0.5) | 1.4 (0.3) | 4.3 (0.5) | 2.2 (0.3)
Health insurance
Any | 20.1 (0.8) | 3.5 (0.3) | 3.0 (0.3) | 13.5 (0.6) | 1.5 (0.3) | 5.0 (0.4) | 2.6 (0.2)
No insurance | 16.7 (2.7) | 4.8 (2.0)^2^ | 0.5 (0.2)^1^ | 10.8 (2.5) | 1.1 (1.0) | 5.4 (1.7) | 5.0 (2.2)
Private | 12.4 (0.7) | 1.8 (0.2) | 2.3 (0.3) | 8.0 (0.4) | 0.8 (0.3) | 2.5 (0.4) | 1.2 (0.2)
Medicare | 38.7 (3.1) | 8.6 (1.9) | 6.2 (1.6) | 28.2 (3.2) | 2.2 (1.1)^2^ | 7.8 (1.5) | 6.2 (1.4)
Medicaid | 35.1 (1.6) | 6.3 (0.7) | 3.4 (0.4) | 24.6 (1.4) | 2.7 (0.6) | 10.5 (1.1) | 6.4 (0.7)
Duration of diabetes (years)
<2 | 18.4 (1.7) | 2.9 (0.6) | 3.7 (0.9) | 12.3 (1.3) | 1.6 (0.8)^2^ | 5.0 (1.0) | 2.7 (0.7)
2–5 | 15.5 (1.2) | 3.0 (0.9) | 1.8 (0.3) | 9.6 (1.1) | 1.1 (0.4)^1^ | 4.2 (0.7) | 2.3 (0.9)^1^
6–15 | 19.1 (1.2) | 2.8 (0.4) | 3.1 (0.4) | 12.4 (0.9) | 1.4 (0.5)^1^ | 4.8 (0.8) | 2.0 (0.3)
>15 | 24.4 (1.7) | 5.9 (0.9) | 2.9 (0.6) | 17.4 (1.5) | 1.2 (0.4)^1^ | 5.6 (0.9) | 3.5 (0.6)
Body mass index (kg/m^2^)
<18.5 | 27.5 (8.0) | ^3^ | 2.3 (1.3) | 21.3 (7.5)^1^ | ^3^ | ^3^ | 10.3 (3.4)
18.5–<25.0 | 14.1 (1.4) | 3.7 (0.9) | 1.9 (0.3) | 8.6 (1.1) | 1.1 (0.2) | 3.3 (0.4) | 1.8 (0.3)
25.0–<30.0 | 14.3 (1.1) | 2.9 (0.4) | 2.7 (0.4) | 8.9 (0.9) | 0.7 (0.1) | 3.2 (0.5) | 1.9 (0.4)
≥30.0 | 23.6 (1.0) | 3.9 (0.5) | 3.2 (0.4) | 16.6 (0.8) | 1.7 (0.4) | 5.6 (0.6) | 3.4 (0.5)
Current smoker
Yes | 29.8 (1.9) | 5.2 (0.9) | 3.4 (0.6) | 22.4 (1.8) | 1.7 (0.5) | 6.9 (1.0) | 3.3 (0.7)
No | 22.4 (1.5) | 4.3 (0.9) | 4.2 (0.8) | 15.0 (1.2) | 0.8 (0.1) | 6.6 (1.1) | 3.1 (0.6)
Coronary heart disease
Yes | 35.9 (5.2) | 4.8 (0.5) | 5.7 (2.2) | 23.8 (4.3) | 1.5 (0.2) | 10.3 (3.3)^1^ | 3.2 (0.4)
No | 18.2 (0.7) | 3.3 (0.4) | 2.6 (0.3) | 11.8 (0.5) | 1.2 (0.3) | 4.5 (0.4) | 2.5 (0.4)
Stroke
Yes | 44.6 (4.6) | 7.6 (2.0) | 5.9 (1.8)^1^ | 32.1 (4.0) | 2.0 (0.4) | 17.0 (3.8) | 10.7 (3.2)
No | 18.3 (0.7) | 3.4 (0.4) | 2.8 (0.3) | 12.0 (0.5) | 1.3 (0.3) | 4.2 (0.4) | 2.3 (0.3)
Cancer
Yes | 29.4 (3.3) | 5.3 (1.6) | 3.7 (0.9) | 22.9 (2.9) | 0.7 (0.2) | 6.6 (1.7) | 4.7 (2.1)^2^
No | 19.1 (0.7) | 3.7 (0.4) | 2.8 (0.3) | 12.5 (0.6) | 1.4 (0.3) | 4.9 (0.4) | 2.8 (0.3)
Arthritis
Yes | 35.6 (2.2) | 7.0 (1.8) | 5.1 (0.9) | 28.6 (2.1) | 1.3 (0.4) | 9.5 (1.3) | 6.8 (1.8)
No | 13.2 (0.7) | 2.7 (0.3) | 2.1 (0.3) | 7.0 (0.5) | 1.4 (0.3) | 3.5 (0.4) | 1.8 (0.2)
Depression
Yes | 36.5 (1.5) | 6.8 (1.0) | 4.9 (0.6) | 25.2 (1.4) | 2.0 (0.4) | 12.1 (1.0) | 6.4 (1.0)
No | 13.5 (0.7) | 2.6 (0.3) | 2.2 (0.2) | 8.7 (0.5) | 1.2 (0.3) | 2.1 (0.3) | 1.5 (0.2)
COPD/emphysema, chronic bronchitis
Yes | 49.0 (3.7) | 7.4 (2.3) | 7.4 (2.4) | 37.6 (4.0) | 2.1 (0.5) | 16.9 (3.2) | 6.3 (1.8)
No | 17.4 (0.7) | 3.3 (0.4) | 2.6 (0.2) | 11.1 (0.5) | 1.3 (0.3) | 4.2 (0.4) | 2.5 (0.3)

Diabetes status and all sociodemographic and health factors are self-reported. Data are age-standardized to the National Health Interview Survey 2019 overall population, using age categories 20–44, 45–64, 65–74, and ≥75 years. COPD, chronic obstructive pulmonary disease; GED, general equivalency diploma.

* Any disability was determined using the Washington Group Short Set Composite Disability Indicator, which includes six functioning domains: vision (difficulty seeing), hearing (difficulty hearing), mobility (difficulty walking or climbing steps), communication (difficulty communicating, including understanding or being understood), cognitive (difficulty remembering or concentrating), and self-care (difficulty with self-care, such as washing all over or dressing). Adults who responded “a lot of difficulty” or “cannot do at all” to at least one functioning domain were considered to have a disability.

† The poverty income ratio is defined as family income divided by the federal poverty threshold.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health Interview Surveys 2019–2022