# Prevalence and Incidence of Type 1 Diabetes Among Children and Adults in the United States and Comparison With Other Countries

## Summary

Type 1 diabetes is one of the most common chronic diseases of childhood in the United States, although it can manifest at any age. In 2017, based on data from the SEARCH for Diabetes in Youth study (SEARCH), the overall prevalence of type 1 diabetes among U.S. youth age <20 years was 215 cases per 100,000 population. Type 1 diabetes prevalence was similar by sex but increased with age. In 2017–2018, the annual incidence of type 1 diabetes in youth <20 years was 22.2 per 100,000, representing an annual increase of 2.02% since 2002–2003. Among non-U.S. youth, the prevalence of type 1 diabetes varies widely and was lowest in Burkina Faso, Africa (1.76 per 100,000 in 2022) and highest in Qatar, in the Middle East (386.2 per 100,000 in 2018–2020). In 2022, the lowest incidence was reported in Burkina Faso, Africa (0.34 per 100,000) and the highest in Sardinia, Italy (76.3 per 100,000).

Compared to data in youth, data on the prevalence and incidence of type 1 diabetes in U.S. adults are very limited. According to the National Health Interview Survey (NHIS), the prevalence of type 1 diabetes in adults age ≥20 years in 2019–2023 was 390 per 100,000 population. The higher prevalence in adults compared to children is expected, as it comprises individuals diagnosed in both childhood and adulthood. Furthermore, recent data suggest that type 1 diabetes incidence in adults may be at least as high as in children, challenging the historical belief that type 1 diabetes is primarily a childhood disease. Specifically, data from a California healthcare system database estimated that the annual incidence in adults age 20–45 years was 30.1 per 100,000 population in 2017 and was higher in men (32.5 per 100,000) compared with women (27.2 per 100,000). Additional studies on incidence in adults are critically needed to better understand the growing burden of type 1 diabetes in the United States. Among non-U.S. regions reporting data on the incidence of type 1 diabetes among adults, overall rates ranged from 3.84 per 100,000 in China (2021) to 32.07 per 100,000 per year in Ireland (2011–2016).

Although vital for determining the burden of type 1 diabetes in the population and guiding effective prevention and control strategies, surveillance of type 1 diabetes faces challenges, particularly given the absence of standardized case definitions and consistent ascertainment methodologies. Administrative and electronic health record databases may serve as tools for estimating diabetes incidence and prevalence; however, while these databases offer promising opportunities, their reliability and validity remain uncertain and require further investigation. Ultimately, standardizing diabetes classification and improving data ascertainment are critical steps toward improving our understanding of the growing burden of type 1 diabetes and developing effective mitigation strategies.

## Introduction

Type 1 diabetes is one of the most common chronic diseases in childhood, although it can manifest at any age. In 2017, type 1 diabetes affected approximately one in every 500 (2.15 per 1,000) youth age <20 years in the United States (1). It accounted for nearly all cases of diabetes in children age <10 years and more than 86% of all cases of diabetes in youth age 10–19 years (1). Every year, more than 18,000 new cases of type 1 diabetes occur in U.S. youth.

Type 1 diabetes primarily results from an autoimmune-mediated destruction of pancreatic β-cells, ultimately leading to complete cessation of insulin secretion and high blood glucose concentrations. People with type 1 diabetes require lifelong exogenous insulin administration for survival. The optimal treatment of type 1 diabetes includes basal insulin and multiple doses of short-acting insulin using injections or an insulin infusion pump, frequent checking or continuous monitoring of blood glucose concentrations, and adjusting insulin doses for carbohydrate intake and physical activity.

Type 1 diabetes imposes significant burden not only on the individual with type 1 diabetes but also on their family and caregivers, particularly when the diagnosis occurs in childhood (2). Despite advances in diabetes management since publication of the results of the Diabetes Control and Complications Trial (DCCT) (3,4), individuals with type 1 diabetes are at risk of both acute (e.g., severe hypoglycemia, diabetic ketoacidosis [DKA]) and chronic (i.e., microvascular and macrovascular disease) complications, and although their life expectancy has increased substantially, it may be shorter than that of the U.S. general population. Because of the often young age at onset, individuals with type 1 diabetes are at high risk of developing diabetes-associated complications at a relatively young age, affecting their quality of life and increasing the risk of premature mortality compared to similarly aged individuals without diabetes (5,6,7). People with type 1 diabetes may also be at increased risk for adverse education and employment outcomes (8). In the United States, the lifetime economic burden attributed to type 1 diabetes compared to the population without type 1 diabetes has been estimated at $813 billion (2016 USD) (9).

This article summarizes epidemiological evidence on the burden of type 1 diabetes in children and adolescents, as well as in adults, in the United States compared to other countries. The summary is based on published original reports that include data from 2015 to 2024 (when our review was completed). While some of these reports also include historical data, their inclusion was contingent on the presence of contemporary data (defined as 2015 or later), offering insights into the evolving burden of this chronic condition across population subgroups. To maximize generalizability, we excluded reports from single healthcare centers, unless evidence of good representativeness was provided (e.g., diabetes centers serving large regions that report high case ascertainment). We also excluded reports describing projection models or simulations. The content herein is an update of the Diabetes in America, 3rd edition, chapter Prevalence and Incidence of Type 1 Diabetes Among Children and Adults in the United States and Comparison With Non-U.S. Countries (10).

## How Is Type 1 Diabetes Defined?

Diabetes mellitus represents a complex group of metabolic disorders characterized by persistent hyperglycemia resulting from impairments in insulin secretion, insulin action, or a combination of both. The classification of diabetes is undergoing reassessment based on specific traits and disease pathophysiological mechanisms (11); however, the vast majority of persons with diabetes are classified as having either type 1 diabetes or type 2 diabetes. In type 1 diabetes, autoimmune-mediated destruction of pancreatic β-cell mass ultimately leads to complete cessation of insulin secretion and the requirement for lifelong exogenous insulin administration. The disease progresses in four stages (12,13). Stage 1 is marked by the presence of two or more autoantibodies against glutamic acid decarboxylase 65 (GAD65), insulin autoantibodies (IAA), protein phosphatase-like islet antigen 2 (IA-2A), zinc transporter 8 (ZnT8), or islet cell cytoplasmic antigen (ICA), normoglycemia, and absence of symptoms (11). Stage 2 is characterized by dysglycemia in the presence of autoimmunity and absence of symptoms. Stage 3 marks the onset of clinical, symptomatic disease, and stage 4 is established, long-term type 1 diabetes. In contrast, type 2 diabetes is usually characterized by insulin resistance and progressive β-cell failure in the absence of evidence of autoimmunity.

While classification of diabetes into a specific clinical type is essential for guiding approaches to management, this categorization can at times be challenging. As an example, symptoms of monogenic diabetes, a less common form of diabetes caused by a single gene mutation, are similar to those of type 1 or type 2 diabetes, yet treatment options differ (14). In cases where uncertainty exists, testing for the presence of one or more diabetes autoantibodies combined with low C-peptide concentration can be used to support the classification of diabetes as type 1 diabetes (11). However, limited resources often prohibit testing for these diagnostic markers; healthcare providers must rely primarily on clinical characteristics for classification of diabetes, which has been shown to lead to high rates of misclassification of diabetes type, especially in older age groups (15). Thus, although provider diagnosis of type 1 diabetes in youth is 96.9% sensitive and 82.8% specific compared with etiologic criteria (16), misclassification increases with older age of diabetes onset (15). Indeed, a study reported that the cause of clinically diagnosed type 1 diabetes was reclassified in 6.8% of adults when serum C-peptide testing was conducted (17). In another study of adults diagnosed with diabetes after age 30 years, almost 40% of those with severe insulin deficiency were misdiagnosed and were not treated with insulin (18).

### Children and Adolescents

Historically, the classification of diabetes has been primarily based on age at onset, with childhood-onset cases typically classified as type 1 diabetes and adult-onset cases as type 2 diabetes. Absolute insulin deficiency, with a requirement for insulin replacement therapy soon after diagnosis, and a lower body mass index (BMI) have also been features typically associated with type 1 diabetes. It is now evident, however, that none of the above attributes are exclusive to a specific diabetes type. Age at onset is an unreliable distinguishing factor, as both type 1 and type 2 diabetes can manifest at any age. In addition, recent studies have suggested a changing phenotype in pediatric type 1 diabetes, with a large proportion of children and adolescents presenting with overweight and obesity (19). These data challenge the assumption that the presence of obesity and its related insulin resistance (20) are reliable indicators of type 2 diabetes. Moreover, while insulin treatment soon after diagnosis remains a hallmark of type 1 diabetes management, youth with type 2 diabetes may also require insulin therapy (21). These observations underscore the complexity of diabetes classification and the need for more sophisticated criteria to distinguish diabetes type. The Diabetes in America article Diabetes in Children and Adolescents (22) also describes the burden of type 1 and type 2 diabetes in children and adolescents, along with other aspects of diabetes in youth, such as risk factors and complications in this age group.

The recognition of heterogeneity in both the underlying biological mechanisms and clinical manifestations of diabetes has led to a growing interest in developing more refined classification criteria based on specific traits and disease pathophysiological mechanisms (23). Heterogeneity is increasingly apparent within type 1 diabetes (24), with subgroups ranging from fulminant forms where there is acute absolute insulin deficiency to the slowly progressing latent autoimmune diabetes in adults (LADA) (25) and a distinct form characterized by absent autoantibodies in certain African populations, as well as in Black Americans (26). These diverse disease manifestations likely reflect the influence of a distinct interplay between environmental and genetic risk factors in the etiology of type 1 diabetes (27). Research focused on identifying endotypes of type 1 diabetes is ongoing and may pave the way for precision medicine approaches to disease management and targeted therapeutic strategies, which could substantially improve outcomes and quality of life.

### Adults

Despite decades of research on diabetes, our knowledge of the incidence of adult-onset type 1 diabetes is still limited. Reasons for this gap include the fact that type 1 diabetes incidence is too rare to be accurately evaluated within existing cohort studies, the lack of a standardized case definition of type 1 diabetes in adults, and the persistence of the inaccurate paradigm that type 1 diabetes only occurs during childhood (28). As more than half of new-onset type 1 diabetes cases occur in adulthood (29,30,31,32) and type 2 diabetes in youth has increased worldwide (33), distinguishing diabetes type is becoming increasingly challenging. The more variable course of type 1 diabetes in adults compared to children further complicates the classification of diabetes type in adults. For example, the need for insulin may progress more slowly in adults. The American Diabetes Association’s Standards of Care in Diabetes recommend islet autoantibody testing in adults presenting with diabetes who present clinical features associated with type 1 diabetes, including younger age, unintentional weight loss, ketoacidosis, or need for insulin within a short timeframe (28). However, although the presence of β-cell antibodies and low C-peptide levels may be useful to confirm type 1 diabetes diagnosis, the sensitivity and specificity of these tests are suboptimal (34), and they are not tested in all people. As discussed, data suggest that misdiagnosis occurs in nearly 40% of adult-onset type 1 diabetes cases, with the risk of error increasing with age (28). This leads to delayed insulin therapy, poorer glycemic control, and risk of DKA, as well as stress from conflicting messages about type and management of diabetes (35). In adult populations, clinical features of type 1 diabetes, type 2 diabetes, and other diabetes subtypes substantially overlap (36,37), and no single clinical feature confirms type 1 diabetes (28).

Surveillance studies of type 1 diabetes incidence that include adult-onset cases have used a variety of case definitions. A U.S. study of young adults in California used a combination of diagnosis codes, laboratory test results, prescription data, and autoantibody markers (38). Studies from China (39) and Spain (40,41) also required autoantibody positivity to classify people as having type 1 diabetes. Other international reports based their definitions on insulin prescription data (42,43,44) or a combination of the diagnosis codes and prescriptions (45,46). Directly comparing type 1 diabetes incidence and prevalence across studies is challenging, particularly for adult populations. One major contributing factor to this difficulty is the lack of a clinical gold standard for determining diabetes type. Therefore, a standardized definition of type 1 diabetes is critically needed to better facilitate comparisons across populations.

## Sources and Limitations of National Data on the Prevalence of Type 1 Diabetes

Two U.S. national surveys, the National Health Interview Survey (NHIS) and the National Health and Nutrition Examination Survey (NHANES), are commonly used to assess the prevalence of diabetes. However, identifying persons with type 1 diabetes in these and other surveys is challenging given some participants’ inability to accurately report their type of diabetes and the lack of routinely collected etiologic biomarker data. Nonetheless, algorithms that can be applied to self-reported survey data have been developed to estimate type 1 diabetes among participants in national surveys. The estimates derived from these data can be weighted, resulting in nationally representative estimates of the U.S. noninstitutionalized population. Additional limitations include that since type 1 diabetes is a relatively rare condition, sample sizes are small and the national surveys only allow for prevalence estimation among adults. In addition, the most recent NHIS and NHANES surveys have had response rates of approximately 50%. While statistical adjustment for nonresponse is incorporated into their sampling weights to mitigate potential bias, some degree of bias may remain, especially when samples are small. Using survey-based algorithms that incorporate diabetes treatment regimen is an improvement over historical methods of determining diabetes type based solely on age at diagnosis (47); however, they may still misclassify some individuals with type 2 diabetes as having type 1 diabetes, or vice versa. The algorithms may also underestimate the prevalence of type 1 diabetes because they exclude people reporting use of oral antihyperglycemic medications, which are increasingly being prescribed to people with type 1 diabetes despite the lack of clinical trial evidence to support this practice (48).

The NHIS is a cross-sectional household interview survey that uses a complex sampling design and has been conducted continuously since 1957. This article utilizes NHIS data collected from individuals for the period 2019–2023 to estimate current prevalence of type 1 diabetes among adults age ≥20 years. Among participants that reported a physician diagnosis of diabetes, type 1 diabetes was presumed if participants self-reported their diabetes as type 1 and additionally reported continuous insulin use within 1 year of diagnosis and current insulin use (49).

The NHANES is a cross-sectional, national probability sample that has been conducted periodically since 1971 and continuously since 1999. This article utilizes the NHANES data collected from individuals for the period 2001–2023 to assess trends and current prevalence of type 1 diabetes among adults age ≥20 years. Type 1 diabetes was defined as self-report of a physician diagnosis of diabetes, current insulin use (and not taking oral antihyperglycemic medications), and initiated insulin treatment within 1 year of diagnosis (47).

## Other U.S. Data Sources for Type 1 Diabetes Prevalence and Incidence

To date, the most comprehensive and rigorous data on type 1 diabetes prevalence and incidence in children and adolescents in the United States come from the SEARCH for Diabetes in Youth study (SEARCH), a registry initiated in 2000 and funded by the Centers for Disease Control and Prevention (CDC) and the National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK). SEARCH used an active surveillance system to identify cases of both type 1 and type 2 diabetes in individuals age <20 years from all major U.S. race/ethnicity groups in specific geographic regions: the states of Colorado, Ohio, South Carolina, and Washington, as well as members of a single large health plan in southern California (Kaiser Permanente) and in selected American Indian reservations in Arizona and New Mexico (50). While SEARCH was not a true national registry, the study’s sociodemographic composition has been shown to reasonably represent U.S. youth at risk for diabetes (51). Cases were identified via rigorous reviews of medical records, and completeness of case ascertainment was assessed using the capture-recapture method for the four geographic regions.

In addition to data from SEARCH, data on the incidence of type 1 diabetes in U.S. children and adolescents were incorporated from studies based on hospital records from Alabama (52) and Utah (53) and from a health insurance database (Kaiser Permanente Southern California) (54). While the hospital databases captured a large proportion of individuals with type 1 diabetes (specifically, 87% ascertainment from a single large healthcare system in Alabama and statewide estimates from two large healthcare systems in Utah), they have limitations. These include the possibilities of incomplete case ascertainment or missing information in the medical records, which may have led to incomplete capture of incident cases; in particular, the exact proportion of cases captured by the Utah study is not reported, implying that the statewide estimates are extrapolations. The health insurance database used in the study by Mefford et al. (54) was representative of the population in Southern California, mitigating concerns about generalizability usually associated with health insurance-based data sources, although the data presented exclude individuals not covered by private insurance.

Other U.S. data sources include the claims databases Clinformatics Data Mart Database (OptumInsight) of 73 million Americans with private insurance (55) and the MarketScan Multi-State Medicaid Database of more than 40 million Medicaid enrollees (56). These data sources are not truly nationwide and have the general limitations associated with claims databases, including reliance on diagnosis and prescription codes, which may result in misclassification of diabetes type.

## Current Surveillance Systems for Type 1 Diabetes

Public health surveillance is the systematic and continuous collection, analysis, and interpretation of health outcome data (57). Public health surveillance is important in assessing the burden and distribution of a health-related issue in the population and identifying its determinants to help guide public health action, including prevention and control efforts. In the United States, the CDC established the Diabetes Surveillance System to monitor the prevalence and incidence of diabetes, as well as its risk factors, complications, and mortality. Given the proportion of the population affected and severity of disease, diabetes surveillance activities are vital in the development and implementation of prevention and intervention strategies for diabetes and its complications.

As described in detail by Saydah et al. (2018) (58), surveillance of type 1 diabetes primarily relies on data from registries, national health surveys, electronic health records, and (less frequently) laboratory data, including measures of insulin sensitivity, genetic markers, or autoimmunity indicators. Each of these data sources may use a different case definition for type 1 diabetes, and each has inherent limitations in estimating the incidence and prevalence of diabetes, as well as in correctly identifying diabetes type. Indeed, the validity and accuracy of data derived from national health surveys rely on the individual’s ability to correctly recall and report their diabetes type. Furthermore, the accuracy of health records depends on the healthcare provider’s ability to correctly identify type of diabetes. While antibodies and genetic markers provide specificity regarding the type of diabetes, misclassification is still possible and not uncommon. Therefore, accurately classifying diabetes type presents a challenge for public health surveillance systems.

Nonetheless, research studies have provided encouraging data regarding the accuracy of surveillance data to classify diabetes type. In the United States, SEARCH investigators assessed the validity and accuracy of both provider-assigned diabetes type (16) and an International Classification of Diseases, Tenth Revision (ICD-10)-based algorithm (59). Provider-assigned diabetes type abstracted from medical records compared favorably against etiologically determined (i.e., based on testing for diabetes autoantibodies and measures of insulin sensitivity) diabetes type, with high sensitivity (96.9%), specificity (82.8%), and positive (97.0%) and negative (82.7%) predictive values for type 1 diabetes (16). The ICD-10 algorithm also performed well, with sensitivity, specificity, and positive predictive values of >95.0%, >96.0%, and >97.0% for type 1 diabetes, respectively (59). In another study using data from the U.S. Department of Defense, researchers successfully developed algorithms to accurately classify diabetes type based on electronic health record (e.g., laboratory values, body weight, blood pressure) and claims data (e.g., ICD, Ninth Revision [ICD-9] diagnostic codes, medication dispensed) in newly diagnosed children (60). Similarly, an algorithm developed based on electronic health records accurately classified diabetes type among children and adults enrolled in the Hong Kong Diabetes Register (61).

To address the separate, but related, challenge of incomplete case ascertainment, “capture-recapture” methods are employed by some registries, including SEARCH. This approach takes advantage of the overlap among multiple independent data sources to estimate the number of cases missed by all sources and, thus, provides a more robust and complete estimate of incidence or prevalence than is possible from a single source.

Collectively, these studies suggest that while diabetes classification remains challenging, well-designed algorithms with good sensitivity and specificity and methods to increase completeness of case ascertainment may improve the validity of surveillance estimates in children and adolescents. Such algorithms enhance the utility of existing healthcare data systems for diabetes surveillance, especially in regions without national surveillance systems.

## Prevalence of Type 1 Diabetes in the U.S. Population Age <20 Years by Age, Sex, and Race/Ethnicity

In 2017, SEARCH reported the prevalence of type 1 diabetes in youth age <20 years to be 2.15 per 1,000 (95% confidence interval [CI] 2.10–2.20) (Table 1) (1). Type 1 diabetes prevalence was similar by sex but increased with age, from 0.28 per 1,000 in children age ≤4 years to 3.93 per 1,000 in children age 15–19 years (Figure 1, Table 1). Among race/ethnicity groups, the prevalence of type 1 diabetes was highest in non-Hispanic White youth (2.79 per 1,000), followed by non-Hispanic Black (2.18 per 1,000), Hispanic (1.56 per 1,000), Asian or Pacific Islander (0.76 per 1,000), and American Indian/Alaska Native (0.56 per 1,000) youth (Figure 1, Table 1).

The population under surveillance by SEARCH is similar to the general U.S. population on several socioeconomic factors (51) and is therefore considered representative of the general U.S. population of youth with type 1 diabetes; however, data are collected from only five states and selected Native American sites, so it is not possible to assess geographic variation in prevalence. A study based on a nationwide database of 73 million Americans with private health insurance between 2001 and 2016 identified an almost fifteenfold difference in the prevalence of type 1 diabetes in youth age ≤19 years among states, with the highest prevalence observed in Vermont (79.6 per 10,000 [95% CI 43.5–133.6]) and the lowest in California (5.4 per 10,000 [95% CI 5.2–5.6]) (55). Despite highlighting important differences among states, the accuracy of these data is questionable, as they rely on administrative claims data to capture cases of type 1 diabetes. Furthermore, these data have limited generalizability to youth without private health insurance.

Within the observation period for SEARCH, the estimated prevalence of type 1 diabetes in youth age <20 years increased significantly from 1.48 per 1,000 (95% CI 1.44–1.52) in 2001 to 2.15 per 1,000 (95% CI 2.10–2.20) in 2017 (Table 1), an absolute increase of 0.67 per 1,000 (95% CI 0.64–0.70) over this period (1); however, that increase was only observed in youth age ≥5 years, while prevalence remained stable across the two periods in younger children (Figure 1). Type 1 diabetes prevalence increased similarly in both male (0.71 per 1,000, 95% CI 0.66–0.75) and female (0.63 per 1,000, 95% CI 0.58–0.67) youth; however, the largest absolute increases were among non-Hispanic White (0.93 per 1,000, 95% CI 0.88–0.98) and non-Hispanic Black (0.89 per 1,000, 95% CI 0.80–0.99) youth (Figure 1).

Similar prevalence estimates of type 1 diabetes, as well as similar overall trends over time, have been provided by a study based on claims data. Using the U.S. MarketScan Commercial Claims and Encounter database, Chen et al. (2019) (56) estimated that the prevalence of type 1 diabetes in the Medicaid population age <18 years rose from 1.29 per 1,000 (95% CI 0.91–1.83) in 2002 to 2.34 per 1,000 (95% CI 1.96–2.79) in 2016 (Table 1). The estimated prevalence of type 1 diabetes was lower in Hispanic and non-Hispanic Black youth compared with non-Hispanic White youth. As in the SEARCH registry, the increased prevalence over time was similar between males and females; however, unlike SEARCH, no race/ethnicity group differences were observed in trends over time. Whether this difference compared to SEARCH may be related to characteristics of the population eligible for Medicaid is unclear. Nonetheless, this increasing trend in the prevalence of type 1 diabetes among youth from both of these U.S. sources likely reflects an increase in incidence (52,53,62).

### Comparison With International Prevalence Rates

Worldwide, the number of youth age <20 years living with type 1 diabetes has been estimated at 1.9 million, including 1.0 million youth age <15 years, in 2025 (63). Several international studies have examined the prevalence of type 1 diabetes in children and youth outside the United States (Table 2).

Most studies have been conducted in Europe, where prevalence estimates ranged from approximately 135 per 100,000 in Serbia in 2019 (64) to 150 in Italy in 2015–2020 (65), 180 in Ireland in 2011–2016 (44), and 240 in Germany in 2018–2019 (66,67). There are few estimates of type 1 diabetes prevalence in non-European regions. A retrospective review of medical records from three regions of Tanzania estimated prevalence ranging from 10 to 12 per 100,000 in youth age <15 years (68). Estimates from prospective program registers in Mali (69) and Burkina Faso (70) were lower at 2.9 and 1.76 per 100,000, respectively, in youth and young adults age <25 years. Those low prevalence rates are partly due to deaths from failure to correctly diagnose and treat type 1 diabetes, something that remains tragically common in low-income countries (30). In contrast, prevalence estimates from a retrospective review of medical records of youth age <20 years in Saudi Arabia (AL-Baha region) (71) and a prospective pediatric diabetes center cohort age <19 years in Qatar (72) were much higher at 355 and 386 per 100,000, respectively. An analysis of national claims data in South Korea estimated a prevalence of 41 per 100,000 in youth age <15 years (73).

## Incidence of Type 1 Diabetes in the U.S. Population Age <20 Years

Globally, more than 200,000 children and young adults age <20 years are diagnosed with type 1 diabetes annually (63). Applying 2017–2018 incidence rates from SEARCH to the total U.S. population, it was estimated that 18,169 children and adolescents are diagnosed with type 1 diabetes in the United States each year (62). Overall, the annual incidence of type 1 diabetes in youth age <20 years within this time period was 22.2 per 100,000 (Table 3) (62). Incidence increased with age from 14.4 per 100,000 among children age 0–4 years to 26.2 per 100,000 among children age 5–9 years and 33.2 per 100,000 among children age 10–14 years, then declined to 14.6 per 100,000 in adolescence (age 15–19 years). Incidence was higher in males compared with females (23.8 vs. 20.6 per 100,000) and in non-Hispanic White youth (26.4), followed by non-Hispanic Black (22.1), Hispanic (17.7), Asian or Pacific Islander (9.4), and American Indian (7.8) youth. Peak incidence occurred at age 10 years, with boys having a later peak (age 12 years, 95% CI 9–13) compared with girls (age 10 years, 95% CI 9–11). Across race/ethnicity groups, peak incidence occurred earlier (at age 9 years) in Hispanic and Asian or Pacific Islander youth, followed by non-Hispanic White and Black youth (at age 10 years for both) and American Indian youth (at age 11 years).

Table 3 includes studies on the incidence of type 1 diabetes in U.S. youth. As seen, there are substantial differences across studies in the time periods of observation, study methods, and the demographic composition of the population studied, making comparison of rates between the SEARCH registry and the other studies challenging. It should also be noted that the California study was based on data from Kaiser Permanente Southern California, which was included in SEARCH, so there is partial data overlap. Nonetheless, the annual incidence of 26.4 per 100,000 observed among non-Hispanic White youth age <20 years in SEARCH in 2017–2018 was similar to incidence rates based on health insurance databases in California (54) and Utah (53), 27.3 and 28.9 per 100,000, respectively, but higher than the 17.0 per 100,000 observed in Alabama in 2000–2017 (52). Additionally, while the Alabama study was conducted in a single clinical center, raising concerns regarding generalizability, approximately 87% of children diagnosed with type 1 diabetes in Alabama received care in that center. Similarly, among non-Hispanic Black youth age <20 years in 2017–2018, the annual incidence of 22.1 per 100,000 in SEARCH was similar to the 27.2 per 100,000 observed in California (54) and the 19.1 per 100,000 in Utah (53), but higher than the 12.4 per 100,000 observed in Alabama (52). In Hispanic youth age <20 years in 2017–2018, the incidence rate of 17.7 per 100,000 in SEARCH was higher than that observed in both California (15.4 per 100,000) (54) and Utah (14.6 per 100,000) (53). In Asian or Pacific Islander youth age <20 years in 2017–2018, the annual incidence of 9.4 per 100,000 in SEARCH was similar to the 8.0 per 100,000 in California (54) but higher than the 5.6 per 100,000 in Utah (53). In contrast, the SEARCH incidence rate of 7.8 per 100,000 among American Indian/Alaska Native youth in 2017–2018 was lower than the 11.1 per 100,000 reported in the study from Utah (53).

### Comparison With International Incidence Rates

Data for European countries, which have historically had higher type 1 diabetes incidence than other regions (63) and thus more plentiful data, are shown in Table 4. Data for other global regions are shown in Table 5. Most recent estimated incidence rates vary widely from a high of 73.9 per 100,000 per year (2019–2022) in Sardinia, Italy, residents age 0–14 years (74) (Table 4) to a low of 0.34 per 100,000 in 2022 in Burkina Faso residents age 0–25 years (70) (Table 5). The differences in reported incidence rates across countries and regions likely reflect variations in population structure and associated underlying genetic risk (75), diagnostic criteria, and the age ranges studied. The variation in incidence may also reflect possible misclassification of youth with type 2 diabetes as type 1 diabetes, which may be more common in some studies versus others.

European countries reported incidence rates ranging from 8.0 to 73.9 cases per 100,000 children per year (Table 4). Finland reported one of the highest rates globally, at 52.2 per 100,000 children age <15 years per year in 2015–2018 (76), although this represented a decrease from 57.9 per 100,000 per year in 2003–2006, primarily driven by lower incidence in children age <5 years. The highest reported incidence was from Sardinia, Italy, with 85.8 per 100,000 age 0–14 years in 2021 (74), where rates have nearly doubled over the past two decades.

The lowest incidence rates were consistently observed in children diagnosed age <5 years, generally about half the rates of those diagnosed after this age. Incidence rates were largely comparable between ages 5 and 18 years (41,77,78), and where reported, incidence rates were generally comparable between sexes.

Reported annual incidence rates vary widely among African countries (Table 5). Most recent incidence rates were highest in Northwest Algeria (79) at 38.5 per 100,000 in youth age <15 years, followed by the west, south, and Tripoli regions of Libya at 31.7 per 100,000 in youth age <15 years (80) and Eritrea at 22.8 per 100,000 in youth and young adults age <25 years (81). Rates in three regions of Tanzania ranged from 1.8 to 1.9 per 100,000 in youth age <15 years (68). Prospective program registers in Mali (69) and Burkina Faso (70) reported much lower incidence rates at 0.74 and 0.34 per 100,000 in those age <25 years. All studies reported a slight male excess, except in Libya and Burkina Faso, where rates were more similar by sex.

In the Middle East (Table 5), the most recent estimated annual incidence rates in Qatar were high at 31.8 per 100,000 in the national pediatric diabetes center register in youth age <15 years (82) and 38.1 per 100,000 in a pediatric diabetes cohort age <19 years (72,83). Most recent estimates from Iran show incidence of 14.5 per 100,000 per year in youth age <20 years, with similar rates by sex (84).

In the Western Pacific region (Table 5), annual incidence rates of type 1 diabetes were similar across Asian countries, ranging from 2.2 per 100,000 in those age <15 years in Henan Province, China (85) to 4.3 per 100,000 in those age <18 years in Hong Kong (86). Studies from China (85) and South Korea (73) reported sex-specific incidence rates, with both observing a slight female excess. The estimated annual incidences from an Australian national register (87) and a Western Australia regional register (88) were similar at 25.0 and 22.9 per 100,000, respectively, in youth age <15 years. National data from New Zealand estimated a similar annual incidence rate of 23 per 100,000 in youth age <15 years (89). Regional data from New Zealand showed incidence in Auckland was similar at 25 per 100,000 (90), while incidence in Canterbury was higher at 36.1 per 100,000 (91).

Few studies have reported incidence of type 1 diabetes in the Americas and the Caribbean (Table 5). The most recent annual incidence estimate from a national public insurance register in Mexico was 2.8 per 100,000 in youth age <20 years (92). A retrospective review of medical records from pediatric endocrinology clinics in the Dominican Republic estimated incidence of 4.2 per 100,000 (93). The only recent study from South America is from a nationwide registry in Chile, which reported an estimated incidence of 12.7 per 100,000 per year in youth age <20 years (94).

### Variations in Incidence by Birth Month and Seasonal Patterns

Seasonal patterns in the diagnosis of type 1 diabetes vary considerably across different world regions. In the United States, data from the SEARCH registry have consistently, over a 17-year period, suggested a significant seasonality pattern in the incidence of type 1 diabetes, with the highest incidence in January and the lowest in June (62). The increase in winter did not appear to coincide with increased health care contact, as August had the highest proportion of cases presenting for routine health care visits. A similar seasonal variation was also observed in Utah (53), with higher incidence rates in the fall and winter months compared to warmer months. Several countries in Europe (45,95,96,97,98,99,100), Africa (80), the Middle East (Qatar (82)) and South America (94) have also reported seasonal variation in type 1 diabetes diagnosis similar to that observed in the United States. In China’s Henan Province, the highest incidence was observed in the summer and autumn, with the lowest occurring in the spring (85). In contrast, the peak incidence in Japan was observed during the spring among youth age 0–19 years (43).

Nonetheless, not all regions have observed seasonal patterns. Studies conducted in Azerbaijan (101), China (39), Korea (73), the Republic of Maldives (102), and Mexico (92) have shown no seasonal variation in type 1 diabetes incidence. Interestingly, in Canterbury, New Zealand, whereas a significant preponderance of cases was seen in the spring and summer between 1970 and 1999, this pattern was no longer detected when analyses were conducted over a longer 50-year period (91).

Taken together, these data show considerable variation in seasonal patterns of type 1 diabetes onset. This variation, coupled with the lack of clear etiologic factors related to season, suggests the observed seasonality may not have a purely biological basis.

### Temporal Trends in Incidence

Data from the SEARCH registry suggest that in youth age <20 years, the age-, sex-, and race/ethnicity-adjusted incidence of type 1 diabetes increased from 19.5 per 100,000 in 2002–2003 to 22.2 per 100,000 in 2017–2018, with an annual increase of 2.02% (95% CI 1.54%– 2.49%) (62). This increase in incidence was highest for males compared to females (2.30% vs. 1.70%) and for minority youth compared with non-Hispanic Whites (4.84% for Asian or Pacific Islander, 4.14% for Hispanic, 2.93% for non-Hispanic Black, 1.79% for American Indian, and 0.60% for non-Hispanic White youth) (Figure 2). The annual percentage change in incidence increased incrementally with age, from 0.56% (95% CI ‑0.48% to 1.61%) in children age 0–4 years to 2.75% (95% CI 1.69%–3.82%) in youth age 15–19 years (Figure 2).

Previous studies have documented an increase in the incidence of type 1 diabetes in Alabama (52) and Utah (53). In Alabama, Correya et al. (2020) (52) reported an age-adjusted annual percentage increase of 3.0% (95% CI 1.4%–4.7%) between 2000 and 2017, higher than that observed in the SEARCH registry. Racial differences in incidence trends did not reach statistical significance (2.8% among White and 4.4% among Black youth, p=0.25). Analyses by sex suggested a significant increase among females (3.6%, p=0.0001) but not among males (2.8%, p=0.06). In Utah, McCullough et al. (2021) (53) documented an increase in incidence from 23.9 per 100,000 in 1998 to 27.98 per 100,000 in 2015, representing an annual increase of 0.80%. However, the authors did not report whether there were differences in incidence trends by sex or race/ethnicity.

Outside the United States, some European studies (95,103,104) reported smaller changes in incidence over approximately the last 10 years, typically within ±3% per year. Larger relative increases (>10% per year) were reported in countries with initially very low incidence, such as Mali (69) and Mexico (92). The rapidly rising incidence in those countries is at least partly due to improvements in diagnosing type 1 diabetes over time, which has reduced deaths from non-diagnosis (30). Estimates across Asia show less variability, with an observed increase of 3%–4% per year in South Korea (2008–2016) (73), 6.6% per year in Henan Province, China (2017–2020) (85), and 4.7% per year in Oita Prefecture, Japan (1999–2021) (105). The only data on temporal trends in the Middle East are from Qatar, where an increase of 3.1% per year was observed (2012–2018) (82).

In contrast to those increases in type 1 diabetes incidence, data from other regions suggest patterns of type 1 diabetes incidence in youth age <20 years may be changing. For example, incidence was increasing 16.1% per year in Mexico between 2000 and 2006 but then began to decrease by ‑8.7% per year until 2018, the most recent year reported (92). These large fluctuations suggest unexplained variability in the data from Mexico, but other global regions have shown similar, albeit less extreme, patterns. For example, data from Auckland, New Zealand, show that incidence was increasing by 2.9% per year from 1977 to 2006 but then began to decease slightly by ‑0.3% per year until 2019 (90). On the other hand, data from Canterbury, New Zealand, show that while incidence increased by 3.9% per year in youth age <15 years overall from 1970 to 2019 (91), it remained stable or even decreased slightly in children age <5 years. Data from the national Australian register show incidence decreased by ‑0.9% per year between 2002 and 2017 (87), with the largest decreases in incidence observed in children younger than 5 years (‑2.5% per year in boys, ‑1.4% per year in girls) (87).

Tables 3, 4, and 5 present studies on the incidence of type 1 diabetes in youth. The Diabetes in America article Risk Factors for Type 1 Diabetes discusses several hypothesized reasons for the increasing incidence of type 1 diabetes worldwide, including possible viral triggers, dietary changes, and exposures to environmental toxins (27).

## Prevalence of Type 1 Diabetes in the U.S. Population Age ≥20 Years

Type 1 diabetes prevalence data in adults are far less abundant than for children and youth. It is important to note that adult prevalence estimates in the United States include a combination of people with type 1 diabetes diagnosed in childhood who have aged into adulthood and people with type 1 diabetes diagnosed in adulthood. Data on incidence of type 1 diabetes in adults age ≥20 years are discussed in the next section.

Using data from the NHIS and defining type 1 diabetes as self-report of diabetes, continuous use of insulin since within 1 year of diabetes diagnosis, and current insulin use, the estimated prevalence of type 1 diabetes in U.S. adults age ≥20 years was 0.39% in 2019–2023 (Table 6). That estimate is close to the prevalence of 0.43% across all ages in the United States in 2021 estimated by the T1D Index, a partnership of several diabetes advocacy organizations, which used mathematical modeling and a machine learning algorithm (106). Prevalence estimates were lower in the older age groups, which may be due to a combination of increased mortality at older ages and the rising incidence of type 1 diabetes observed in younger age groups over recent decades (52,53,62). The estimated prevalence was higher in men than in women. Race and ethnicity differences were also observed, with the highest prevalences observed in non-Hispanic White and American Indian/Alaska Native adults and the lowest in Hispanic adults.

Type 1 diabetes prevalence in U.S. adults was also examined in the NHANES (Figure 3, Table 7). Defining type 1 diabetes as self-report of diabetes, initiation of insulin within 1 year of diabetes diagnosis, and current insulin use only (no oral agents), the estimated prevalence among U.S. adults age ≥20 years was 0.66% in 2017–2023 and was greater in men than in women (Table 7). Compared to 2001–2008, the estimated prevalence of type 1 diabetes increased with increasing age among those 20–39 and 40–59 years, whereas prevalence in the ≥60-years age group remained relatively stable (Figure 3). Race and ethnicity differences in type 1 diabetes prevalence were apparent, with prevalence increasing over time in non-Hispanic White adults, remaining relatively stable in non-Hispanic Black adults, and decreasing in Hispanic adults (Figure 3).

There are notable differences in sampling and diabetes case ascertainment approaches between the NHIS and NHANES. The NHIS primarily samples households and then individuals within them, whereas the NHANES directly samples individuals. Additionally, the NHANES oversamples individuals with household incomes below 130% of the federal poverty level, a practice not employed by the NHIS. However, both surveys are weighted to provide estimates generalizable to the U.S. noninstitutionalized population. The most significant factor influencing the prevalence estimates presented here is how each survey identifies diabetes type, with NHIS relying on self-report and NHANES applying an algorithm to the data that defines type 1 diabetes. The NHIS directly asks participants to report their diabetes type, which likely underestimates the true prevalence of type 1 diabetes, as many people are not aware of their specific diabetes type (49). In contrast, the NHANES does not ask the diabetes type, so type 1 diabetes status is derived from an algorithm based on self-report of any diabetes and continuous insulin use (47). While that approach avoids the pitfalls of self-reporting diabetes type, it introduces another challenge. The CDC reports that 12.3% of adults with all diabetes types initiate insulin within a year of diagnosis, yet only 5.7% of adults with diabetes self-report having type 1 diabetes (107). Thus, the NHANES estimate likely includes people with type 2 diabetes who are using insulin.

The true prevalence of type 1 diabetes in the U.S. population likely lies somewhere between the estimates provided by the NHIS and NHANES. The discrepancy highlights the critical need for a dedicated national diabetes surveillance system to obtain the most accurate picture of the burden of diabetes in the United States.

### Comparison With International Prevalence Rates

Table 8 summarizes estimates of type 1 diabetes prevalence in adults in regions in Europe. The prevalence of type 1 diabetes ranges from lowest prevalences of 0.17% and 0.20% per year in females and males, respectively, among those age 25–34 years in Greece (108) to 0.74% per year in those age ≥75 years in Ireland (44); both studies used a definition of type 1 diabetes based on pharmacy claims. Surprisingly, these data from Greece and Ireland suggest the prevalence of type 1 diabetes in older adults is as high as it is the whole population. In other European regions/countries, such as Wales (45) and Denmark (109), the prevalences of type 1 diabetes are similar, ranging from 0.3% to 0.5% across all ages (0–99 years).

## Incidence of Type 1 Diabetes in the U.S. Population Age ≥20 Years

Compared to data in children and adolescents, there is a paucity of data on the incidence of type 1 diabetes in adults, and there are vast differences in case definitions. Table 9 summarizes estimates of type 1 diabetes incidence in adults. While historically such data arose mainly from Europe, particularly Scandinavian countries, more recent data have emerged from other world regions, especially Asia.

The only study on incidence of type 1 diabetes in U.S. adults published since 2015 was conducted in a California healthcare system database and analyzed 2,347,989 people age 20–45 years in 2017 (38). The study used diagnosis codes, lab results, and dispensed insulin prescription data to determine diabetes diagnosis. Testing for pancreatic islet autoantibodies was performed on 25% of identified persons with diabetes who consented to participate in the study and provided blood samples, whereas antibody status was imputed for the remainder. Individuals with one or more positive diabetes autoantibodies were classified as having type 1 diabetes. The estimated annual incidence was 30.1 per 100,000 overall and higher in men (32.5 per 100,000) than in women (27.2 per 100,000) (Table 9). While the major strengths of this study include its large, racially and ethnically diverse population and detailed electronic health record data, its results may not be generalizable to the U.S. adult population as it represents a single healthcare system; thus, additional studies are critically needed.

### Comparison With International Incidence Rates

In the Western Pacific region, data on type 1 diabetes incidence in adults are limited to two studies, one from Japan (43) and another from China (110) (Table 9). The annual incidence varied considerably, ranging from 3.82 per 100,000 (age ≥30 years) in China in 2015 (110) to ≥5.0 per 100,000 in those age 40–59 years in Japan in 2014–2017 (43). When sex-specific data were available, incidence was higher in men compared to women. In China, incidence increased by 3% between 2007 and 2018 (110). In adults, incidence was higher in Japan (43), but this study used a less stringent definition of type 1 diabetes. There is a lack of high-quality data on incidence of type 1 diabetes in adults in other regions outside of Europe.

European data on type 1 diabetes incidence in adults are slightly more plentiful (Table 9). Incidence data from the United Kingdom in those age 15–29 years was lower than other parts of Europe and stable over time, ranging from 5.3 per 100,000 per year in 2000–2002 to 5.9 per 100,000 per year in 2017–2019, but higher in men versus women (111). Type 1 diabetes incidence in Scotland, defined using a pharmacy claims algorithm (42), is at least double that in the whole of the United Kingdom (111) and Spain (40), ranging from 32.0 to 21.7 per 100,000 per year in men and women age 15–29 years, respectively, and decreasing to 10.0 and 8.3 per 100,000 per year in men and women age ≥50 years, respectively. The definition used in the Scottish data (42) encompassed two levels of type 1 diabetes definition: probable and possible; when the rates were calculated only using the more stringent “probable” definition, the incidence halved in those age ≥50 years. This study also showed a predominance of type 1 diabetes incidence in men compared to women, supporting findings from Spain (40). Data from Wales (45) are similar to the Scottish data (42). Among adults, the highest incidence was observed in those age 15–29 years at 26.87 per 100,000 per year (45); the definition used in this study was complex and comprised a combination of hospital and general practitioner codes, plus insulin use within 12 months of diagnosis and/or a DKA episode.

In Serbia, among younger adults between ages 20 and 29 years, the incidence in 2006–2017 ranged between 8.2 and 8.4 per 100,000 per year using a clinical definition of diabetes (112). Using registry data from the Piedmont type 1 diabetes registry in Italy, Giorda et al. (113) reported incidence in a young-adult population age 15–29 years at 10.44 per 100,000 per year in 2017–2019 and 12.52 per 100,000 per year in 2020–2022.

Data from Spain in adult age groups come from two regions: Navarre (40) and Asturias (41). These data were derived from whole-of-region diabetes registries. Of note, the definitions of type 1 diabetes applied in these Spanish studies included presence of diabetes autoantibodies, low C-peptide, and insulin use within 1 year. From the registry in Navarre (40), incidence in young adults was 17.4 and 9.1 per 100,000 per year in men and women age 15–29 years, respectively. The higher incidence in adult men was consistent with previous reports from the region, but interestingly there were no significant sex differences in those ages 10–14 (Table 4) or ≥45 years (Table 9). The authors attributed the predominance of type 1 diabetes incidence in males compared to females due to possible hormonal influence on insulin resistance, different lifestyles, and/or genetic predisposition (40). In the study using data from the Asturias region (41), the incidence in the total population in the same adult age groups was 11.1 per 100,000 per year. Incidence of type 1 diabetes decreased with increasing age in both studies (40,41).

Data from Scandinavia come from Sweden (114) and Denmark (46), which reported different incidence rates. In Sweden, among a young adult population age 18–37 years, incidence was 18.8 per 100,000 per year and higher in men compared to women (114). In Denmark, using a definition of type 1 diabetes that included insulin use and a hospital discharge with a type 1 diabetes code, incidence in 2021 ranged from 28.5 per 100,000 in the first quarter to 31.6 per 100,000 in the second quarter (46).

Similarly high incidence of type 1 diabetes in adults was observed in data from Ireland (44). Among Irish adults age 15–24 years, incidence per year in 2011–2016 was 26.89 per 100,000 and increased to 41.23 and 54.15 per 100,000 in those ages 65–74 and ≥75 years, respectively. Incidence was 1.3-fold higher in men than in women. The magnitude of incidence in Ireland and the fact that incidence increased with age suggest possible misclassification of people with type 2 diabetes as type 1 diabetes in these data. In this study, a treatment-based definition was used to define diabetes type (coprescription of insulin and glucometer test strips without a long-term course of oral hypoglycemic agents prior to starting insulin).

Altogether, these data on type 1 diabetes incidence in adults reported in the last 10 years show that when a pharmacy claim-based definition is used, incidence in the same age groups can differ considerably across countries compared to when a more stringent definition is used. Further, the possibility of type 1 diabetes estimates being contaminated with people with type 2 diabetes increases with age (115). Type 2 diabetes is estimated to account for >95% of diabetes mellitus in the United States and >98% worldwide and is much more common than type 1 diabetes in adult age groups (106). Thus, even small errors in the classification of type 2 diabetes might have a large effect on the reported incidence of type 1 diabetes. Such misclassification might explain the discrepancies between studies reporting incidence of type 1 diabetes in older adults, as discussed in a recent review (115). As we noted in the section on prevalence of type 1 diabetes in adults, this misclassification could also lead to inflated prevalence estimates. These data clearly highlight the need to work towards better methods of defining and ascertaining data on type 1 diabetes in adults.

### Temporal Trends in Incidence

Findings on temporal trends in type 1 diabetes incidence in the adult population have been highly variable. Data arising from a whole-of-population regional registry in Spain suggest that incidence of type 1 diabetes in adults was stable from 2011 to 2020 (40). Data from Serbia show that incidence in adults age 20–29 years decreased over the period of 2006–2017 (112), and incidence of type 1 diabetes in Taiwanese adults show a slight increasing trend over the period of 2005–2014 (116).

## Incidence of Type 1 Diabetes Before and After the COVID-19 Pandemic

While there has been speculation that the COVID-19 (coronavirus disease of 2019) pandemic period may have been associated with an increase in the incidence of type 1 diabetes, most published literature shows no significant difference compared to the pre-COVID-19 period, although data are mixed (Table 10). Specifically, data from Oita Prefecture of Japan (105), the Hubei Province of China (117), Thailand (118), and Western Australia (88) reported similar incidence rates in the years preceding the pandemic through the end of 2022. In contrast, data from Kaiser Permanente Southern California suggest that the incidence of type 1 diabetes increased from 18.09 per 100,000 in 2016–2019 to 21.13 per 100,000 in 2020–2021 (54). Similarly, data from Chile’s nationwide register suggest a significant increase in type 1 diabetes incidence from 11.7 per 100,000 per year in 2006–2019 to 20.2 per 100,000 per year in 2020–2021 (94).

In youth and young adults, an increase in incidence from 10.55 per 100,000 per year in 2017–2019 (before the COVID-19 pandemic) to 12.52 per 100,000 per year in 2020–2022 (after the COVID-19 pandemic) was reported from the Piedmont type 1 diabetes registry in Italy (113). A Danish study also reported a slight increase in incidence, from 24–28 per 100,000 per year prior to the COVID-19 pandemic to between 23 and 32 per 100,000 per year in the post-COVID-19 period (2020–2021) (Table 10) (46). Data from a Chinese study reported that type 1 diabetes incidence increased from 2.77 in 2007 to 3.84 per 100,000 persons in 2021; however, type 1 diabetes incidence was stable from 2019 to 2021 (110).

There are general limitations of the research examining the potential impact of COVID-19 on type 1 diabetes incidence, including that the data were collected and reported during different waves of the pandemic, as well as difficulties with separating out the potential effect of infection itself versus containment strategies, such as lockdowns (119). Longer-term data will be needed to determine whether the observed increases in type 1 diabetes incidence have continued or if the rates have returned to prepandemic levels.

## Future for Surveillance of Type 1 Diabetes

In establishing an accurate and reliable surveillance system for type 1 diabetes, several important challenges must be carefully considered. A critical first step would be the development of an accurate, precise, universally accepted, and consistent case definition for classification of type 1 diabetes. Whether different criteria should be applied for children and adolescents compared to adults should also be considered. Careful consideration should be given to defining the surveillance population and whether it should be population-based within a geographic area or confined to a specific healthcare or hospital system. The sustainability of surveillance efforts, including time and cost considerations, is important for maintaining operations over time.

In addition to registries and national surveys, the past decade has witnessed growing interest in the use of electronic health records and claims data for monitoring the prevalence and incidence of type 1 diabetes, particularly because of the relatively low cost of accessing existing data. As described earlier, researchers have developed algorithms to identify and classify diabetes type using administrative data and electronic health records, often with considerable accuracy (59,60). However, their validity in identifying diabetes type in adults requires further investigation.

To address this issue, the Diabetes in Children, Adolescents, and Young Adults (DiCAYA) Network was established (120), comprising eight clinical centers across the United States. This network includes both youth (age <18 years) and young adults (age 18–44 years) and aims to validate the use of electronic health record-based algorithms for identifying prevalent and incident cases of both type 1 and type 2 diabetes. DiCAYA investigators developed a “computable phenotype” using information contained in the electronic health record to determine diabetes type, which achieved >90% sensitivity and specificity in classifying type 1 diabetes (121), demonstrating the feasibility of using electronic health record-based surveillance. However, as a single surveillance system is unlikely to provide comprehensive and accurate estimates (58), a more practical approach may be to combine data from multiple existing systems to achieve more accurate estimates. A new initiative from the CDC, the Comprehensive Analysis, Surveillance, and Statistics Initiative for Diabetes in the Young (CASSIDY), has been designed to accomplish this objective and will build upon the knowledge gained and limitations revealed by DiCAYA to “establish a systematic, comprehensive, and sustainable surveillance system capable of providing timely information on the burden of diabetes among youth and young adults in the United States” (122).

## Conclusions and Future Directions

It is clear that type 1 diabetes poses a significant and growing health burden, but a number of gaps exist in understanding its full impact and temporal trends in the U.S. population. A major challenge remains the lack of standardized case definitions, which impedes comparisons of prevalence and incidence rates across health care systems, diverse population subgroups, and different time periods. The adoption of a common set of questions in national surveys focusing on initiation of continuous insulin treatment and age could provide a basic, albeit limited, estimate of national prevalence. Importantly, clear, simplified guidelines are needed to help distinguish type 1 diabetes from type 2 diabetes to avoid misclassification, a major problem for adult-onset diabetes that is also becoming increasingly problematic for childhood-onset diabetes.

Further investigation is needed to understand the continuing increase in type 1 diabetes incidence among U.S. youth, especially the higher risk in males. Additionally, while Black youth continue to have lower incidence rates of type 1 diabetes compared to their White counterparts, they experienced a greater relative increase in incidence since 2009. Potential reasons for that apparent acceleration in type 1 diabetes risk warrant careful study. Furthermore, international data from the past decade suggest type 1 diabetes prevalence and incidence may be greater in non-European ancestry populations than previously recognized, underscoring the need for more comprehensive data and careful assessment of diverse populations.

Data from the last decade on type 1 diabetes incidence in adults reveal considerable intercountry variation, especially comparing estimates derived from pharmacy claims to those based on stricter clinical criteria. Given that type 2 diabetes is far more prevalent in adults, even minor classification errors can significantly inflate reported type 1 diabetes prevalence and incidence estimates. Therefore, improved methods for defining type 1 diabetes, along with consistent monitoring of its prevalence and incidence in both youth and in adults, are essential for effective healthcare planning and evaluation of secondary prevention strategies. Ultimately, closing these critical data gaps and standardizing diabetes classification are fundamental steps toward developing effective strategies to mitigate the growing burden of type 1 diabetes.

## List of Abbreviations

CDC: Centers for Disease Control and Prevention
CI: confidence interval
COVID-19: coronavirus disease of 2019
DiCAYA: Diabetes in Children, Adolescents, and Young Adults Network
DKA: diabetic ketoacidosis
ICD-9/10: International Classification of Diseases, Ninth/Tenth Revision
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
SEARCH: SEARCH for Diabetes in Youth study

## Funding

Drs. Miller and Costacou are supported by a grant funded by the National Institute of Diabetes and Digestive and Kidney Diseases and administered by the National Heart, Lung, and Blood Institute (HL161879) and a grant funded by the American Diabetes Association (7-23-ICTSWH-19). Dr. Costacou is additionally supported by the National Institute of Diabetes and Digestive and Kidney Diseases-funded grant U01DK094157. Dr. Magliano is supported by the National Health and Medical Research Council Investigator fellowship. Dr. Thomas is a Gillings funded academic clinical lecturer at the University of Exeter.

## Acknowledgment

This is an update of: Imperatore G, Mayer-Davis EJ, Orchard TJ, Zhong VW. Prevalence and Incidence of Type 1 Diabetes Among Children and Adults in the United States and Comparison With Non-U.S. Countries. Chapter 2 in Diabetes in America, 3rd edition. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institute of Health, NIH Pub No. 17-1468, 2018, p. 2.1–2.17

## Article History

Received in final form September 17, 2025.

## References

1 Lawrence JM, Divers J, Isom S, et al. Trends in prevalence of type 1 and type 2 diabetes in children and adolescents in the US, 2001–2017. JAMA. 2021;326(8):717-727. doi:10.1001/jama.2021.11165 34427600
2 Azimi T, Johnson J, Campbell SM, Montesanti S. Caregiver burden among parents of children with type 1 diabetes: a qualitative scoping review. Heliyon. 2024;10(6):e27539. doi:10.1016/j.heliyon.2024.e27539 38524615
3 Diabetes Control and Complications Trial Research Group, Nathan DM, Genuth S, et al. The effect of intensive treatment of diabetes on the development and progression of long-term complications in insulin-dependent diabetes mellitus. N Engl J Med. 1993;329(14):977-986. doi:10.1056/NEJM199309303291401 8366922
4 Braffett BH, Bebu I, Lorenzi GM, et al. The NIDDK takes on the complications of type 1 diabetes: the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) study. Diabetes Care. 2025;48(7):1089-1100. doi:10.2337/dc24-2885 40272271
5 Ruiz PLD, Chen L, Morton JI, et al. Mortality trends in type 1 diabetes: a multicountry analysis of six population-based cohorts. Diabetologia. 2022;65(6):964-972. doi:10.1007/s00125-022-05659-9 35314870
6 Miller RG, Secrest AM, Sharma RK, Songer TJ, Orchard TJ. Improvements in the life expectancy of type 1 diabetes: the Pittsburgh Epidemiology of Diabetes Complications study cohort. Diabetes. 2012;61(11):2987-2992. doi:10.2337/db11-1625 22851572
7 Hallström S, Wijkman MO, Ludvigsson J, et al. Risk factors, mortality trends and cardiovascular diseases in people with type 1 diabetes and controls: a Swedish observational cohort study. Lancet Reg Health Eur. 2022;21:100469. doi:10.1016/j.lanepe.2022.100469 35898332
8 Fleming M, Fitton CA, Steiner MFC, et al. Educational and health outcomes of children treated for type 1 diabetes: Scotland-wide record linkage study of 766,047 children. Diabetes Care. 2019;42(9):1700-1707. doi:10.2337/dc18-2423 31308017
9 Sussman M, Benner J, Haller MJ, Rewers M, Griffiths R. Estimated lifetime economic burden of type 1 diabetes. Diabetes Technol Ther. 2020;22(2):121-130. doi:10.1089/dia.2019.0398 31886730
10 Imperatore G, Mayer-Davis EJ, Orchard TJ, Zhong VW. Prevalence and incidence of type 1 diabetes among children and adults in the United States and comparison with non-U.S. countries. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018; p. 2.1-2.17:chap 2. https://www.ncbi.nlm.nih.gov/books/NBK568003/
11 Sacks DB, Arnold M, Bakris GL, et al. Guidelines and Recommendations for Laboratory Analysis in the Diagnosis and Management of Diabetes Mellitus. Diabetes Care. 2023;46(10):e151-e199. doi:10.2337/dci23-0036 37471273
12 Insel RA, Dunne JL, Atkinson MA, et al. Staging presymptomatic type 1 diabetes: a scientific statement of JDRF, the Endocrine Society, and the American Diabetes Association. Diabetes Care. 2015;38(10):1964-1974. doi:10.2337/dc15-1419 26404926
13 Haller MJ, Bell KJ, Besser REJ, et al. ISPAD Clinical Practice Consensus Guidelines 2024: Screening, Staging, and Strategies to Preserve Beta-Cell Function in Children and Adolescents with Type 1 Diabetes. Horm Res Paediatr. 2024;97(6):529-545. doi:10.1159/000543035 39662065
14 Salguero MV, Arosemena M, Pollin T, et al. Monogenic forms of diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597414/
15 Thomas NJ, Jones AG. The challenges of identifying and studying type 1 diabetes in adults. Diabetologia. 2023;66(12):2200-2212. doi:10.1007/s00125-023-06004-4 37728732
16 Crume TL, Hamman RF, Isom S, et al. The accuracy of provider diagnosed diabetes type in youth compared to an etiologic criteria in the SEARCH for Diabetes in Youth Study. Pediatr Diabetes. 2020;21(8):1403-1411. doi:10.1111/pedi.13126 32981196
17 Foteinopoulou E, Clarke CAL, Pattenden RJ, et al. Impact of routine clinic measurement of serum C-peptide in people with a clinician-diagnosis of type 1 diabetes. Diabet Med. 2021;38(7):e14449. doi:10.1111/dme.14449 33131101
18 Thomas NJ, Lynam AL, Hill AV, et al. Type 1 diabetes defined by severe insulin deficiency occurs after 30 years of age and is commonly treated as type 2 diabetes. Diabetologia. 2019;62(7):1167-1172. doi:10.1007/s00125-019-4863-8 30969375
19 Xu Y, Echouffo Tcheugui JB, Coresh J, et al. Trends in obesity and glucagon-like peptide-1 receptor agonist prescriptions in type 1 diabetes in the United States. Diabetes Obes Metab. 2025;27(6):2967-2976. doi:10.1111/dom.16300 40028670
20 Specht BJ, Wadwa RP, Snell-Bergeon JK, Nadeau KJ, Bishop FK, Maahs DM. Estimated insulin sensitivity and cardiovascular disease risk factors in adolescents with and without type 1 diabetes. J Pediatr. 2013;162(2):297-301. doi:10.1016/j.jpeds.2012.07.036 22921593
21 Badaru A, Klingensmith GJ, Dabelea D, et al. Correlates of treatment patterns among youth with type 2 diabetes. Diabetes Care. 2014;37(1):64-72. doi:10.2337/dc13-1124 24026554
22 Braffett BH, Crume T, Bjornstad P, Dabelea D. Diabetes in children and adolescents. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2025. https://www.ncbi.nlm.nih.gov/books/NBK619869/
23 Leslie RD, Ma RCW, Franks PW, Nadeau KJ, Pearson ER, Redondo MJ. Understanding diabetes heterogeneity: key steps towards precision medicine in diabetes. Lancet Diabetes Endocrinol. 2023;11(11):848-860. doi:10.1016/S2213-8587(23)00159-6 37804855
24 Weston CS, Boehm BO, Pozzilli P. Type 1 diabetes: a new vision of the disease based on endotypes. Diabetes Metab Res Rev. 2024;40(2):e3770. doi:10.1002/dmrr.3770 38450851
25 Redondo MJ, Morgan NG. Heterogeneity and endotypes in type 1 diabetes mellitus. Nat Rev Endocrinol. 2023;19(9):542-554. doi:10.1038/s41574-023-00853-0 37337007
26 Katte JC, McDonald TJ, Sobngwi E, Jones AG. The phenotype of type 1 diabetes in sub-Saharan Africa. Front Public Health. 2023;11:1014626. doi:10.3389/fpubh.2023.1014626 36778553
27 Stene LC, Norris JM, Rewers MJ. Risk factors for type 1 diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597412/
28 American Diabetes Association Professional Practice Committee. 2. Diagnosis and Classification of Diabetes: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S27-S49. doi:10.2337/dc25-S002 39651986
29 Green A, Hede SM, Patterson CC, et al. Type 1 diabetes in 2017: global estimates of incident and prevalent cases in children and adults. Diabetologia. 2021;64(12):2741-2750. doi:10.1007/s00125-021-05571-8 34599655
30 Gregory GA, Robinson TIG, Linklater SE, et al. Global incidence, prevalence, and mortality of type 1 diabetes in 2021 with projection to 2040: a modelling study. Lancet Diabetes Endocrinol. 2022;10(10):741-760. doi:10.1016/S2213-8587(22)00218-2 36113507
31 Rogers MAM, Kim C, Banerjee T, Lee JM. Fluctuations in the incidence of type 1 diabetes in the United States from 2001 to 2015: a longitudinal study. BMC Med. 2017;15(1):199. doi:10.1186/s12916-017-0958-6 29115947
32 Thunander M, Petersson C, Jonzon K, et al. Incidence of type 1 and type 2 diabetes in adults and children in Kronoberg, Sweden. Diabetes Res Clin Pract. 2008;82(2):247-255. doi:10.1016/j.diabres.2008.07.022 18804305
33 Perng W, Conway R, Mayer-Davis E, Dabelea D. Youth-onset type 2 diabetes: the epidemiology of an awakening epidemic. Diabetes Care. 2023;46(3):490-499. doi:10.2337/dci22-0046 36812420
34 Ziegler A-G, Nepom GT. Prediction and pathogenesis in type 1 diabetes. Immunity. 2010;32(4):468-478. doi:10.1016/j.immuni.2010.03.018 20412757
35 Leslie RD, Evans-Molina C, Freund-Brown J, et al. Adult-onset type 1 diabetes: current understanding and challenges. Diabetes Care. 2021;44(11):2449-2456. doi:10.2337/dc21-0770 34670785
36 Ahlqvist E, Storm P, Käräjämäki A, et al. Novel subgroups of adult-onset diabetes and their association with outcomes: a data-driven cluster analysis of six variables. Lancet Diabetes Endocrinol. 2018;6(5):361-369. doi:10.1016/S2213-8587(18)30051-2 29503172
37 Kovacs A, Bunduc S, Veres DS, et al. One third of cases of new-onset diabetic ketosis in adults are associated with ketosis-prone type 2 diabetes. A systematic review and meta-analysis. Diabetes Metab Res Rev. 2024;40(3):e3743. doi:10.1002/dmrr.3743 37888894
38 Lawrence JM, Slezak JM, Quesenberry C, et al. Incidence and predictors of type 1 diabetes among younger adults aged 20–45 years: the Diabetes in Young Adults (DiYA) study. Diabetes Res Clin Pract. 2021;171:108624. doi:10.1016/j.diabres.2020.108624 33338552
39 Liu C, Yuan YC, Guo MN, et al. Incidence of type 1 diabetes may be underestimated in the Chinese population: evidence from 21.7 million people between 2007 and 2017. Diabetes Care. 2021;44(11):2503-2509. doi:10.2337/dc21-0342 34413068
40 Goñi Iriarte MJ, Brugos Larumbe A, Guillén Grima F, Sainz de Los Terreros Errea A, Chueca Guendulain MJ, Forga Llenas L. Incidence of type 1 diabetes in Navarra, 2009–2020. Evidence of a stabilization. Endocrinol Diabetes Nutr (Engl Ed). 2023;70(2):80-87. doi:10.1016/j.endien.2023.02.005 36890019
41 Rodríguez Escobedo R, Delgado Álvarez E, Menéndez Torre EL. Incidence of type 1 diabetes mellitus in Asturias (Spain) between 2011 and 2020. Endocrinol Diabetes Nutr (Engl Ed). 2023;70(3):189-195. doi:10.1016/j.endien.2023.03.008 36966090
42 Thomson I, Anderson N, Bath L, et al. Type 1 diabetes incidence in Scotland between 2006 and 2019. Diabet Med. 2023;40(8):e15069. doi:10.1111/dme.15069 36786040
43 Nishioka Y, Noda T, Okada S, et al. Incidence and seasonality of type 1 diabetes: a population-based 3-year cohort study using the National Database in Japan. BMJ Open Diabetes Res Care. 2020;8(1):e001262. doi:10.1136/bmjdrc-2020-001262 32994226
44 Gajewska KA, Biesma R, Sreenan S, Bennett K. Prevalence and incidence of type 1 diabetes in Ireland: a retrospective cross-sectional study using a national pharmacy claims data from 2016. BMJ Open. 2020;10(4):e032916. doi:10.1136/bmjopen-2019-032916 32312725
45 Rafferty J, Stephens JW, Atkinson MD, et al. A retrospective epidemiological study of type 1 diabetes mellitus in Wales, UK between 2008 and 2018. Int J Popul Data Sci. 2021;6(1):1387. doi:10.23889/ijpds.v6i1.1387 34007896
46 Zareini B, Sørensen KK, Eiken PA, et al. Association of COVID-19 and development of type 1 diabetes: a Danish nationwide register study. Diabetes Care. 2023;46(8):1477-1482. doi:10.2337/dc23-0428 37276529
47 Mosslemi M, Park HL, McLaren CE, Wong ND. A treatment-based algorithm for identification of diabetes type in the National Health and Nutrition Examination Survey. Cardiovasc Endocrinol Metab. 2020;9(1):9-16. doi:10.1097/XCE.0000000000000189 32104786
48 Maffei P, Bettini S, Busetto L, Dassie F. SGLT2 inhibitors in the management of type 1 diabetes (T1D): an update on current evidence and recommendations. Diabetes Metab Syndr Obes. 2023;16:3579-3598. doi:10.2147/DMSO.S240903 37964939
49 Casagrande SS, Lessem SE, Orchard TJ, et al. Comparison of several survey-based algorithms to ascertain type 1 diabetes among US adults with self-reported diabetes. BMJ Open Diabetes Res Care. 2020;8(2):e001917. doi:10.1136/bmjdrc-2020-001917 33298431
50 Hamman RF, Bell RA, Dabelea D, et al. The SEARCH for Diabetes in Youth study: rationale, findings, and future directions. Diabetes Care. 2014;37(12):3336-3344. doi:10.2337/dc14-0574 25414389
51 Pettitt DJ, Talton J, Dabelea D, et al. Prevalence of diabetes in U.S. youth in 2009: the SEARCH for Diabetes in Youth study. Diabetes Care. 2014;37(2):402-408. doi:10.2337/dc13-1838 24041677
52 Correya TA, Ashraf AP, Griffin R, et al. Temporal trends in incidence of pediatric type 1 diabetes in Alabama: 2000–2017. Pediatr Diabetes. 2020;21(1):40-47. doi:10.1111/pedi.12927 31591761
53 McCullough ML, Wan N, Pezzolesi MG, et al. Type 1 diabetes incidence among youth in Utah: a geographical analysis. Soc Sci Med. 2021;278:113952. doi:10.1016/j.socscimed.2021.113952 33933801
54 Mefford MT, Wei R, Lustigova E, Martin JP, Reynolds K. Incidence of diabetes among youth before and during the COVID-19 pandemic. JAMA Netw Open. 2023;6(9):e2334953. doi:10.1001/jamanetworkopen.2023.34953 37733344
55 Rogers MAM, Rogers BS, Basu T. Prevalence of type 1 diabetes among people aged 19 and younger in the United States. Prev Chronic Dis. 2018;15:E143. doi:10.5888/pcd15.180323 30468421
56 Chen Y, Wang T, Liu X, Shankar RR. Prevalence of type 1 and type 2 diabetes among US pediatric population in the MarketScan Multi-State Database, 2002 to 2016. Pediatr Diabetes. 2019;20(5):523-529. doi:10.1111/pedi.12842 30861241
57 Porta M, ed. A Dictionary of Epidemiology. 6th ed. Oxford University Press; 2014. doi:10.1093/acref/9780199976720.001.0001
58 Saydah S, Imperatore G. Emerging approaches in surveillance of type 1 diabetes. Curr Diab Rep. 2018;18(9):61. doi:10.1007/s11892-018-1033-1 29995215
59 Wells BJ, Lenoir KM, Wagenknecht LE, et al. Detection of diabetes status and type in youth using electronic health records: the SEARCH for Diabetes in Youth study. Diabetes Care. 2020;43(10):2418-2425. doi:10.2337/dc20-0063 32737140
60 Teltsch DY, Fazeli Farsani S, Swain RS, et al. Development and validation of algorithms to identify newly diagnosed type 1 and type 2 diabetes in pediatric population using electronic medical records and claims data. Pharmacoepidemiol Drug Saf. 2019;28(2):234-243. doi:10.1002/pds.4728 30677205
61 Ke C, Stukel TA, Luk A, et al. Development and validation of algorithms to classify type 1 and 2 diabetes according to age at diagnosis using electronic health records. BMC Med Res Methodol. 2020;20(1):35. doi:10.1186/s12874-020-00921-3 32093635
62 Wagenknecht LE, Lawrence JM, Isom S, et al. Trends in incidence of youth-onset type 1 and type 2 diabetes in the USA, 2002–18: results from the population-based SEARCH for Diabetes in Youth study. Lancet Diabetes Endocrinol. 2023;11(4):242-250. doi:10.1016/S2213-8587(23)00025-6 36868256
63 Ogle GD, Wang F, Haynes A, et al. Global type 1 diabetes prevalence, incidence, and mortality estimates 2025: results from the International Diabetes Federation Atlas, 11th Edition, and the T1D Index Version 3.0. Diabetes Res Clin Pract. 2025;225:112277. doi:10.1016/j.diabres.2025.112277
64 Stankovic S, Vukovic R, Vorgucin I, et al. First report on the nationwide prevalence of paediatric type 1 diabetes in Serbia and temporal trends of diabetes ketoacidosis at diagnosis—a multicentre study. J Pediatr Endocrinol Metab. 2020;34(2):225-229. doi:10.1515/jpem-2020-0405 33544544
65 Maffeis C, Mancioppi V, Piona C, Avossa F, Fedeli U, Marigliano M. Type 1 diabetes prevalence and incidence rates in the pediatric population of Veneto Region (Italy) in 2015–2020. Diabetes Res Clin Pract. 2021;179:109020. doi:10.1016/j.diabres.2021.109020 34437942
66 Baechle C, Stahl-Pehe A, Prinz N, et al. Prevalence trends of type 1 and type 2 diabetes in children and adolescents in North Rhine-Westphalia, the most populous federal state in Germany, 2002–2020. Diabetes Res Clin Pract. 2022;190:109995. doi:10.1016/j.diabres.2022.109995 35853531
67 Stahl-Pehe A, Kamrath C, Prinz N, et al. Prevalence of type 1 and type 2 diabetes in children and adolescents in Germany from 2002 to 2020: a study based on electronic health record data from the DPV registry. J Diabetes. 2022;14(12):840-850. doi:10.1111/1753-0407.13339 36515004
68 Jasem D, Majaliwa ES, Ramaiya K, Najem S, Swai ABM, Ludvigsson J. Incidence, prevalence and clinical manifestations at onset of juvenile diabetes in Tanzania. Diabetes Res Clin Pract. 2019;156:107817. doi:10.1016/j.diabres.2019.107817 31425767
69 Sandy JL, Besançon S, Sidibé AT, Minkailou M, Togo A, Ogle GD. Rapid increases in observed incidence and prevalence of type 1 diabetes in children and youth in Mali, 2007–2016. Pediatr Diabetes. 2021;22(4):545-551. doi:10.1111/pedi.13191 33586301
70 Sagna Y, Bagbila W, Sawadogo N, et al. Incidence, prevalence, and mortality of type 1 diabetes in children and youth in Burkina Faso 2013–2022. Diabetes Res Clin Pract. 2024;207:111086. doi:10.1016/j.diabres.2023.111086 38181985
71 Al-Ghamdi AH, Fureeh AA. Prevalence and clinical presentation at the onset of type 1 diabetes mellitus among children and adolescents in AL-Baha region, Saudi Arabia. J Pediatr Endocrinol Metab. 2018;31(3):269-273. doi:10.1515/jpem-2017-0059 29537213
72 Haris B, Saraswathi S, Al-Khawaga S, et al. Epidemiology, genetic landscape and classification of childhood diabetes mellitus in the State of Qatar. J Diabetes Investig. 2021;12(12):2141-2148. doi:10.1111/jdi.13610 34101350
73 Chae HW, Seo GH, Song K, et al. Incidence and prevalence of type 1 diabetes mellitus among Korean children and adolescents between 2007 and 2017: an epidemiologic study based on a national database. Diabetes Metab J. 2020;44(6):866-874. doi:10.4093/dmj.2020.0212 33142054
74 Ripoli C, Ricciardi MR, Angelo MR, et al. Incidence of type 1 diabetes in Sardinian children aged 0–14 years has almost doubled in the last twenty years. On top of the world. Diabetes Res Clin Pract. 2024;213:111750. doi:10.1016/j.diabres.2024.111750 38885745
75 Michalek DA, Tern C, Zhou W, et al. A multi-ancestry genome-wide association study in type 1 diabetes. Hum Mol Genet. 2024;33(11):958-968. doi:10.1093/hmg/ddae024 38453145
76 Parviainen A, But A, Siljander H, Knip M, Finnish Pediatric Diabetes Register. Decreased incidence of type 1 diabetes in young Finnish children. Diabetes Care. 2020;43(12):2953-2958. doi:10.2337/dc20-0604 32998988
77 Passanisi S, Salzano G, Aloe M, et al. Increasing trend of type 1 diabetes incidence in the pediatric population of the Calabria region in 2019–2021. Ital J Pediatr. 2022;48(1):66. doi:10.1186/s13052-022-01264-z 35509062
78 Bukara-Radujkovic G, Miljkovic V, Ljuboja O. Evidence of increasing incidence of type 1 diabetes and ketoacidosis among children in the Republic of Srpska in period 2017–2022 with special focus on COVID-19 global pandemic years. Front Public Health. 2023;11:1264099. doi:10.3389/fpubh.2023.1264099 37736091
79 Khater S, Aouar A, Bensmain N, et al. Very high incidence of type 1 diabetes among children aged under 15 years in Tlemcen, Northwest Algeria (2015–2018). J Clin Res Pediatr Endocrinol. 2021;13(1):44-51. doi:10.4274/jcrpe.galenos.2020.2020.0073 32938578
80 Khashebi RM, Patterson CC, Shebani MS. The incidence trend of type 1 diabetes among children and adolescents 0–14 years of age in the west, south, and Tripoli regions of Libya (2009–2018). J Clin Res Pediatr Endocrinol. 2023;15(4):356-364. doi:10.4274/jcrpe.galenos.2023.2023-1-17 37218134
81 Mebrahtu G, Maniam J, James S, Ogle GD. High incidence of type 1 diabetes in adolescents and young adults in Eritrea. Diabet Med. 2021;38(7):e14544. doi:10.1111/dme.14544 33587788
82 Alyafei F, Soliman A, Alkhalaf F, et al. Incidence of type 1 and type 2 diabetes, between 2012–2016, among children and adolescents in Qatar. Acta Biomed. 2018;89(S5):7-10. doi:10.23750/abm.v89iS4.7360 30049926
83 Haris B, Ahmed I, Syed N, et al. Clinical features, epidemiology, autoantibody status, HLA haplotypes and genetic mechanisms of type 1 diabetes mellitus among children in Qatar. Sci Rep. 2021;11(1):18887. doi:10.1038/s41598-021-98460-4 34556755
84 Hashemipour M, Maracy M, Javanmard SH, Zamaneh F, Mostofizadeh N, Hovsepian S. Trends in incidence rates of childhood type 1 diabetes mellitus: a retrospective study in Isfahan province, Iran. J Diabetes Investig. 2023;14(3):376-386. doi:10.1111/jdi.13975 36695001
85 Chen Q, Xu N, Chen Y, et al. Incidence of newly diagnosed type 1 diabetes mellitus in children and adolescents in Henan Province of China from 2017 to 2020: a retrospective multicenter study based on hospitalization data. J Clin Res Pediatr Endocrinol. 2022;14(3):287-292. doi:10.4274/jcrpe.galenos.2022.2022-12-4 35438270
86 Tung JY-L, Kwan EY-W, But BW-M, et al. Increasing incidence of type 1 diabetes among Hong Kong children and adolescents: the Hong Kong Childhood Diabetes Registry 2008 to 2017. Pediatr Diabetes. 2020;21(5):713-719. doi:10.1111/pedi.13016 32267057
87 Haynes A, Bulsara MK, Bergman P, et al. Incidence of type 1 diabetes in 0 to 14 year olds in Australia from 2002 to 2017. Pediatr Diabetes. 2020;21(5):707-712. doi:10.1111/pedi.13025 32304132
88 Zhang S, Mittinty M, Davis EA, Cameron E, Haynes A. Childhood-onset type 1 diabetes in Western Australia: an update on incidence and temporal trends from 2001 to 2022. Diabet Med. 2023;40(11):e15148. doi:10.1111/dme.15148 37191883
89 Wu R, Burnside M, Davies H, et al. Prevalence and incidence of type 1 diabetes in children aged 0–14 years old in New Zealand in 2021. J Paediatr Child Health. 2023;59(3):519-525. doi:10.1111/jpc.16342 36708362
90 Flint SA, Gunn AJ, Hofman PL, et al. Evidence of a plateau in the incidence of type 1 diabetes in children 0–4 years of age from a regional pediatric diabetes center; Auckland, New Zealand: 1977–2019. Pediatr Diabetes. 2021;22(6):854-860. doi:10.1111/pedi.13236 34018288
91 Willis J, Cunningham-Tisdall C, Griffin C, et al. Type 1 diabetes diagnosed before age 15 years in Canterbury, New Zealand: a 50 year record of increasing incidence. Pediatr Diabetes. 2022;23(3):301-309. doi:10.1111/pedi.13305 34954856
92 Wacher NH, Gómez-Díaz RA, Ascencio-Montiel IJ, Rascón-Pacheco RA, Aguilar-Salinas CA, Borja-Aburto VH. Type 1 diabetes incidence in children and adolescents in Mexico: data from a nation-wide institutional register during 2000–2018. Diabetes Res Clin Pract. 2020;159:107949. doi:10.1016/j.diabres.2019.107949 31794808
93 Morla E, Ibrahim A, Ogle GD, et al. Incidence of type 1 diabetes in children in Dominican Republic, 2010–2019: a national collaborative study. Pediatr Diabetes. 2022;23(7):976-981. doi:10.1111/pedi.13380 35689539
94 Tampe I, Garfias C, Borzutzky A, Slaibe L, García H. Incidence of type 1 diabetes in Chilean children between 2006 and 2021: significant increase during the COVID-19 pandemic. Acta Diabetol. 2024;61(1):29-34. doi:10.1007/s00592-023-02163-3 37578530
95 McKenna A, O’Regan M, Ryder K, Fitzgerald H, Hoey H, Roche E. Incidence of childhood type 1 diabetes mellitus in Ireland remains high but no longer rising. Acta Paediatr. 2021;110(7):2142-2148. doi:10.1111/apa.15836 33690888
96 Maltoni G, Zioutas M, Mosticchio M, et al. A comparative study on the incidence of type 1 diabetes mellitus between children of North African migrants and Italian children in Emilia-Romagna region, Italy. Eur J Pediatr. 2022;181(4):1523-1529. doi:10.1007/s00431-021-04340-4 35028726
97 Baechle C, Eckert A, Kamrath C, et al. Incidence and presentation of new-onset type 1 diabetes in children and adolescents from Germany during the COVID-19 pandemic 2020 and 2021: current data from the DPV Registry. Diabetes Res Clin Pract. 2023;197:110559. doi:10.1016/j.diabres.2023.110559 36758641
98 Roche EF, McKenna AM, O’Regan M, Ryder KJ, Fitzgerald HM, Hoey HMCV. The incidence of type 1 diabetes in children under 15 years of age is rising again—a nationwide study. Eur J Pediatr. 2023;182(10):4615-4623. doi:10.1007/s00431-023-05125-7 37550598
99 Esen I, Okdemir D. Trend of type 1 diabetes incidence in children between 2009 and 2019 in Elazig, Turkey. Pediatr Diabetes. 2020;21(3):460-465. doi:10.1111/pedi.12984 31951309
100 Özalkak Ş, Yıldırım R, Tunç S, et al. Revisiting the annual incidence of type 1 diabetes mellitus in children from the Southeastern Anatolian region of Turkey: a regional report. J Clin Res Pediatr Endocrinol. 2022;14(2):172-178. doi:10.4274/jcrpe.galenos.2021.2021-10-7 35014245
101 Ahmadov GA, Govender D, Atkinson MA, et al. Epidemiology of childhood-onset type 1 diabetes in Azerbaijan: incidence, clinical features, biochemistry, and HLA-DRB1 status. Diabetes Res Clin Pract. 2018;144:252-259. doi:10.1016/j.diabres.2018.09.009 30218742
102 Majeed NA, Shiruhana SA, Maniam J, Eigenmann CA, Siyan A, Ogle GD. Incidence, prevalence and mortality of diabetes in children and adolescents aged under 20 years in the Republic of Maldives. J Paediatr Child Health. 2020;56(5):746-750. doi:10.1111/jpc.14726 31868263
103 Tumini S, Baki S, Kosteria I, Di Giuseppe I, Levantini G. Incidence of type 1 diabetes and factors associated with presence and severity of ketoacidosis at onset in children. Acta Biomed. 2022;93(1):e2022009. doi:10.23750/abm.v93i1.11694 35315412
104 Rami-Merhar B, Hofer SE, Fröhlich-Reiterer E, Waldhoer T, Fritsch M, Austrian Diabetes Incidence Study Group. Time trends in incidence of diabetes mellitus in Austrian children and adolescents <15 years (1989–2017). Pediatr Diabetes. 2020;21(5):720-726. doi:10.1111/pedi.13038 32410357
105 Matsuda F, Itonaga T, Maeda M, Ihara K. Long-term trends of pediatric type 1 diabetes incidence in Japan before and after the COVID-19 pandemic. Sci Rep. 2023;13(1):5803. doi:10.1038/s41598-023-33037-x 37037893
106 Ogle GD, Gregory GA, Wang F, et al. The T1D Index: implications of initial results, data limitations, and future development. Curr Diab Rep. 2023;23(10):277-291. doi:10.1007/s11892-023-01520-4 37610700
107 Centers for Disease Control and Prevention. National Diabetes Statistics Report, 2024. Department of Health and Human Services. 2024. Accessed August 20, 2025, https://www.cdc.gov/diabetes/php/data-research/index.html
108 Liatis S, Dafoulas GE, Kani C, et al. The prevalence and treatment patterns of diabetes in the Greek population based on real-world data from the nation-wide prescription database. Diabetes Res Clin Pract. 2016;118:162-167. doi:10.1016/j.diabres.2016.06.018 27372056
109 Carstensen B, Rønn PF, Jørgensen ME. Prevalence, incidence and mortality of type 1 and type 2 diabetes in Denmark 1996–2016. BMJ Open Diabetes Res Care. 2020;8(1):e001071. doi:10.1136/bmjdrc-2019-001071 32475839
110 Liu C, Guo MN, Chai Z, et al. Association between COVID-19 vaccination and incidence of type 1 diabetes in China: evidence from 14.14 million registered residents between 2007 and 2021. Diabetes Res Clin Pract. 2023;201:110723. doi:10.1016/j.diabres.2023.110723 37209876
111 Conrad N, Misra S, Verbakel JY, et al. Incidence, prevalence, and co-occurrence of autoimmune disorders over time and by age, sex, and socioeconomic status: a population-based cohort study of 22 million individuals in the UK. Lancet. 2023;401(10391):1878-1890. doi:10.1016/S0140-6736(23)00457-9 37156255
112 Vojislav C, Natasa R, Milica P, et al. Incidence trend of type 1 diabetes mellitus in Serbia. BMC Endocr Disord. 2020;20(1):34. doi:10.1186/s12902-020-0504-y 32151244
113 Giorda CB, Gnavi R, Tartaglino B, et al. Increased incidence of type 1 diabetes in 2 years of COVID-19 pandemic. Acta Diabetol. 2023;60(4):587-589. doi:10.1007/s00592-022-01986-w 36527501
114 Amadou C, Wei Y, Feychting M, Carlsson S. Early-life factors associated with adult-onset type 1 diabetes: a Swedish nationwide cohort and family-based study. Diabetes Care. 2024;47(10):1740-1749. doi:10.2337/dc24-0896 39046992
115 Tomic D, Harding JL, Jenkins AJ, Shaw JE, Magliano DJ. The epidemiology of type 1 diabetes mellitus in older adults. Nat Rev Endocrinol. 2025;21(2):92-104. doi:10.1038/s41574-024-01046-z 39448829
116 Sheen Y-J, Hsu C-C, Jiang Y-D, Huang C-N, Liu J-S, Sheu WH-H. Trends in prevalence and incidence of diabetes mellitus from 2005 to 2014 in Taiwan. J Formos Med Assoc. 2019;118 Suppl 2:S66-S73. doi:10.1016/j.jfma.2019.06.016 31300322
117 Wu S, Gao Y, Guo S, et al. Characterization of newly diagnosed type 1 diabetes in children and adolescents from 2017 to 2022 in China: a single-center analysis. BMC Pediatr. 2024;24(1):13. doi:10.1186/s12887-023-04498-w 38178064
118 Sinthuprasith P, Wejaphikul K, Puttawong D, et al. Incidences of newly diagnosed childhood diabetes and onset severity: a multicenter regional study in Thailand over two decades and during the COVID-19 pandemic. J Pediatr Endocrinol Metab. 2024;37(6):487-496. doi:10.1515/jpem-2024-0042 38615333
119 D’Souza D, Empringham J, Pechlivanoglou P, Uleryk EM, Cohen E, Shulman R. Incidence of diabetes in children and adolescents during the COVID-19 pandemic: a systematic review and meta-analysis. JAMA Netw Open. 2023;6(6):e2321281. doi:10.1001/jamanetworkopen.2023.21281 37389869
120 Hirsch AG, Conderino S, Crume TL, et al. Using electronic health records to enhance surveillance of diabetes in children, adolescents and young adults: a study protocol for the DiCAYA Network. BMJ Open. 2024;14(1):e073791. doi:10.1136/bmjopen-2023-073791 38233060
121 Shao H, Thorpe LE, Islam S, et al. Developing a computable phenotype for identifying children, adolescents, and young adults with diabetes using electronic health records in the DiCAYA Network. Diabetes Care. 2025;48(6):914-921. doi:10.2337/dc24-1972 40163581
122 HigherGov. Comprehensive Analysis, Surveillance, and Statistics Initiative for Diabetes in the Young (CASSIDY). RFA-DP-25-043. 2024. Accessed October 28, 2025. https://www.highergov.com/grant-opportunity/comprehensive-analysis-surveillance-and-statistics-initiative-for-diabetes-in-355034/
123 Forga L, Tamayo I, Chueca M, et al. Incidence of type 1 diabetes mellitus in Navarre stabilized in the last eight years. Endocrinol Diabetes Nutr (Engl Ed). 2018;65(5):274-279. doi:10.1016/j.endinu.2018.01.003 29555552
124 Raicevic M, Samardzic M, Soldatovic I, Curovic Popovic N, Vukovic R. Trends in nationwide incidence of pediatric type 1 diabetes in Montenegro during the last 30 years. Front Endocrinol (Lausanne). 2022;13:991533. doi:10.3389/fendo.2022.991533 36147568
125 Manuwald U, Schoffer O, Kugler J, et al. Trends in incidence and prevalence of type 1 diabetes between 1999 and 2019 based on the Childhood Diabetes Registry of Saxony, Germany. PLoS One. 2021;16(12):e0262171. doi:10.1371/journal.pone.0262171 34972197
126 Stahl-Pehe A, Baechle C, Lanzinger S, et al. Trends in the incidence of type 1 diabetes and type 2 diabetes in children and adolescents in North Rhine-Westphalia, Germany, from 2002 to 2022. Diabetes Metab. 2024;50(5):101567. doi:10.1016/j.diabet.2024.101567 39095014
127 Fernández-Ramos C, Arana-Arri E, Vela A, Urrutia I, Santos Zorrozua B, Rica I. Increased incidence of pediatric type 1 diabetes during the pandemic in Biscay, Spain. Endocrinol Diabetes Nutr (Engl Ed). 2024;71(8):332-339. doi:10.1016/j.endien.2024.09.002 39374995
128 Podolakova K, Barak L, Jancova E, Stanik J, Podracka L. Increasing incidence of type 1 diabetes mellitus in young children in Slovakia. Bratisl Lek Listy. 2020;121(2):129-132. doi:10.4149/BLL_2020_017 32115965
129 Gesuita R, Rabbone I, Marconi V, et al. Trends and cyclic variation in the incidence of childhood type 1 diabetes in two Italian regions over 33 years and during the COVID-19 pandemic. Diabetes Obes Metab. 2023;25(6):1698-1703. doi:10.1111/dom.15024 36810862
130 Vukovic R, Jesic MD, Vorgucin I, et al. First report on the nationwide incidence of type 1 diabetes and ketoacidosis at onset in children in Serbia: a multicenter study. Eur J Pediatr. 2018;177(8):1155-1162. doi:10.1007/s00431-018-3172-4 29774417
131 Dündar İ, Akıncı A, Çamtosun E, Kayaş L, Çiftçi N, Özçetin E. Type 1 diabetes incidence trends in a cohort of Turkish children and youth. Turk Arch Pediatr. 2023;58(5):539-545. doi:10.5152/TurkArchPediatr.2023.23036 37670553
132 Hayes L, Cheetham T, Muirhead C, et al. Type 1 diabetes in North East England and North Cumbria: patterns and time trends in 0–14-year-olds from 2012 to 2020. Front Public Health. 2023;11:1193403. doi:10.3389/fpubh.2023.1193403 37637832
133 Ortiz-Marrón H, Del Pino Valero V, Esteban-Vasallo M, Zorrilla Torras B, Ordobás Gavín M. Evolution of the incidence of type 1 diabetes mellitus in the Community of Madrid, 1997–2016. An Pediatr (Engl Ed). 2021;95(4):253-259. doi:10.1016/j.anpede.2020.08.011
134 Vlad A, Serban V, Timar R, et al. Increased incidence of type 1 diabetes during the COVID-19 pandemic in Romanian children. Medicina (Kaunas). 2021;57(9):973. doi:10.3390/medicina57090973 34577896
135 Vorgučin I, Savin M, Stanković Đ, et al. Incidence of type 1 diabetes mellitus and characteristics of diabetic ketoacidosis in children and adolescents during the first two years of the COVID-19 pandemic in Vojvodina. Medicina (Kaunas). 2022;58(8):1013. doi:10.3390/medicina58081013 36013479
136 Weiss A, Donnachie E, Beyerlein A, Ziegler AG, Bonifacio E. Type 1 diabetes incidence and risk in children with a diagnosis of COVID-19. JAMA. 2023;329(23):2089-2091. doi:10.1001/jama.2023.8674 37213115
137 Kamrath C, Rosenbauer J, Eckert AJ, et al. Incidence of type 1 diabetes in children and adolescents during the COVID-19 pandemic in Germany: results from the DPV Registry. Diabetes Care. 2022;45(8):1762-1771. doi:10.2337/dc21-0969 35043145

FIGURE 1.

Prevalence of Type 1 Diabetes in Youth Age <20 Years, by Age, Sex, and Race and Hispanic Ethnicity, the SEARCH for Diabetes in Youth Study, U.S., 2001 and 2017.

The SEARCH registry includes Colorado, Ohio, South Carolina, and Washington state, as well as members of a single large health plan in southern California (Kaiser Permanente) and selected American Indian reservations in Arizona and New Mexico. Error bars represent 95% confidence intervals. AIAN, American Indian/Alaska Native; API, Asian or Pacific Islander; NHB, non-Hispanic Black; NHW, non-Hispanic White.

* Signifies statistically significant difference in prevalence between 2001 and 2017.

SOURCE: Reference (1)

Bar graph showing the prevalence of type 1 diabetes in youth is higher in 2017 compared to 2001 for youth 5 years of age and older, both males and females, and for all race and ethnicity subgroups.

FIGURE 2.

Adjusted Annual Percentage Change in Incidence of Type 1 Diabetes in Youth Age <20 Years, by Age, Sex, and Race and Hispanic Ethnicity, the SEARCH for Diabetes in Youth Study, U.S., 2002–2003 and 2017–2018.

The SEARCH registry includes Colorado, Ohio, South Carolina, and Washington state, as well as members of a single large health plan in southern California (Kaiser Permanente) and selected American Indian reservations in Arizona and New Mexico. Data are adjusted for age, sex, and race or ethnicity. Error bars represent 95% confidence intervals. AIAN, American Indian/Alaska Native; API, Asian or Pacific Islander; NHB, non-Hispanic Black; NHW, non-Hispanic White.

SOURCE: Reference (62)

Bar graph showing that the annual percent change in incidence of type 1 diabetes in youth was highest for youth age 15 to 19 years, males, and Asian or Pacific Islander youth but all age, sex and race and ethnicity subgroups had positive percent changes in incidence of type 1 diabetes.

FIGURE 3.

Prevalence of Type 1 Diabetes Among Adults Age ≥20 Years, U.S., 2001–2008 and 2017–2023.

Error bars represent 95% confidence errors. NHB, non-Hispanic Black; NHW, non-Hispanic White.

SOURCE: National Health and Nutrition Examination Surveys 2001–2008 and 2017–2023

Bar graph showing that the prevalence of type 1 diabetes in adults has increased between 2001 and 2023 for adults 20-59 years, both men and women, and for non-Hispanic White adults.

TABLE 1.

Prevalence of Type 1 Diabetes in Youth, by Age, Sex, and Race/Ethnicity, U.S.

YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | PREVALENCE (95% CI) | RELATIVE INCREASE PER YEAR (95% CI)
2001–2016 (55) | ≤19 | Nationwide claims database, Clinformatics Data Mart Database (OptumInsight) | Clinical diagnosis | The prevalence of type 1 diabetes across the 50 states ranged from 5.4 per 10,000 (95% CI 5.2–5.6) in California to 79.6 per 10,000 (95% CI 43.5–133.6) in Vermont.
2002–2016 (56) | <18 | Medicaid claims database (MarketScan Multi-State Medicaid Database) | Clinical diagnosis | Per 1,000 2002: 1.29 (0.91–1.83) 2003: 1.58 (1.17–2.15) 2004: 1.83 (1.39–2.42) 2005: 1.92 (1.48–2.49) 2006: 1.93 (1.48–2.52) 2007: 1.92 (1.45–2.53) 2008: 1.98 (1.52–2.59) 2009: 2.04 (1.60–2.60) 2010: 1.97 (1.54–2.53) 2011: 2.13 (1.66–2.73) 2012: 1.94 (1.55–2.43) 2013: 2.09 (1.69–2.60) 2014: 2.29 (1.91–2.75) 2015: 2.32 (1.95–2.76) 2016: 2.34 (1.96–2.79) | The observed increasing trend in prevalence was similar by sex and race/ethnicity, although prevalence was lower in Black and Hispanic youth compared with non-Hispanic White youth.
2001, 2009, 2017 (1) | <20 | SEARCH registry* | Clinical diagnosis | Per 1,000 [underlined: 2001] 1.48 (1.44–1.52) Males: 1.48 (1.43–1.54) Females: 1.48 (1.42–1.54) [underlined: 2009] 1.93 (1.88–1.98) Males: 1.93 (1.86–1.99) Females: 1.93 (1.87–2.00) [underlined: 2017] 2.15 (2.10–2.20) Males: 2.19 (2.13–2.26) Females: 2.11 (2.04–2.18) Age (years): ≤4: 0.28 (0.24–0.31) 5–9: 1.33 (1.26–1.41) 10–14: 2.91 (2.80–3.02) 15–19: 3.93 (3.81–4.06) Race/ethnicity: Non-Hispanic White: 2.79 (2.72–2.87) Non-Hispanic Black: 2.18 (2.04–2.33) Hispanic: 1.56 (1.48–1.64) Asian or Pacific Islander: 0.76 (0.67–0.85) American Indian: 0.56 (0.43–0.73) | [underlined: 2001–2009] 3.4% (2.9%–3.8%) Males: 3.3% (2.7%–4.0%) Females: 3.4% (2.7%–4.1%) [underlined: 2009–2017] 1.4% (1.0%–1.8%) Males: 1.6% (1.0%–2.2%) Females: 1.1% (0.5%–1.7%)

CI, confidence interval; SEARCH, SEARCH for Diabetes in Youth study.

* The SEARCH registry includes Colorado, Ohio, South Carolina, and Washington state, as well as members of a single large health plan in southern California (Kaiser Permanente) and selected American Indian reservations in Arizona and New Mexico.

SOURCE: References are listed within the table.

TABLE 2.

Prevalence of Type 1 Diabetes in Non-U.S. Youth

COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | PREVALENCE PER 100,000 (95% CI)
Africa
Mali, 2007–2016 (69) | <25 | Prospective program register | Clinical diagnosis | 2007: 0.43 (0.33–0.59) 2016: 2.90 (2.60–3.22)
Tanzania, 2010–2016 (68) | <15 | Retrospective review of medical records | Clinical diagnosis | Dar es Salaam: 10.7 Kilimanjaro: 11.9 Zanzibar: 10.1
Burkina Faso, 2013–2022 (70) | <25 | Prospective program register | Clinical diagnosis | 2013: 0.27 (0.19–0.37) 2022: 1.76 (1.56–1.99)
Middle East and North Africa
Saudi Arabia / AL-Baha region, 2007–2016 (71) | <20 | Retrospective review of medical records | Clinical diagnosis | 355
Qatar, 2018–2020 (72,83) | <19 | Prospective pediatric diabetes center cohort | Clinical diagnosis plus biomarkers | 386.2 (354.9–419.6)
Europe
Serbia, 2000–2019 (64) | <19 | All regional centers that provide health care to individuals with T1D in Serbia | Clinical diagnosis | [underlined: Age (years)] <19: 135.25 0–4.9: 19.1 5–9.9: 100.27 10–14.9: 202.68 15–18.9: 227.5
Germany, 2002–2020 (66) | 0–19 | North Rhine-Westphalia Diabetes Registry | Clinical diagnosis | 2015: 233.0 (227.9–238.2) 2016: 237.2 (232.0–242.4) 2017: 237.4 (232.2–242.6) 2018: 240.3 (235.0–245.5) 2019: 243.5 (238.2–248.7) 2020: 246.9 (241.6–252.2)
Germany, 2002–2020 (67) | <20 | Diabetes Prospective Follow-up Registry | Clinical diagnosis | 2002: 145.9 (144.1–147.7) 2008: 210.7 (208.5–213.0) 2014: 247.9 (245.4–250.5) 2020: 245.6 (243.1–248.0) [underlined: 2020] Boys: 252.2 (248.7–255.8) Girls: 238.5 (235.0–242.0) Age (years): 0–4: 35.0 (33.2–36.9) 5–9: 156.8 (152.9–160.9) 10–14: 341.7 (335.8–347.7) 15–19: 456.4 (449.7–463.2)
U.K. / Wales, 2008–2018 (42) | 0–60 | SAIL Databank | Clinical diagnosis and medications | Age ≤14 years: 180 (170–200)
Ireland, 2011–2016 (44) | <15 | Irish population (per the 2016 Central Statistics Office) | Clinical diagnosis and prescription records | Age 0–4 years: 180 (180–190)
Greece, 2014–2015 (108) | All ages | National Organization for Health Care Services Provision database | Clinical diagnosis | [underlined: Age (years)] <15: 80 Males: 0–4: 10 5–14: 120 Females: 0–4: 20 5–14: 110
Italy / Veneto Region, 2015–2020 (65) | ≤18 | Population data derived from the National Institute for Statistics | Clinical diagnosis and medications | 152.5
Western Pacific Region
South Korea, 2007–2017 (73) | <15 | National claims data | Clinical diagnosis | 2007: 32.9 (31.7–34.1) 2017: 41.0 (39.5–42.6)

International data are organized by International Diabetes Federation (IDF)-defined regions. CI, confidence interval; T1D, type 1 diabetes.

SOURCE: References are listed within the table.

TABLE 3.

Incidence of Type 1 Diabetes in Youth, by Race/Ethnicity, U.S.

REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | INCIDENCE CASES/100,000/YEAR (95% CI)
REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | Overall | Males | Females
All Race/Ethnicity Groups
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | [underlined: Age (years)] 0–19: 25.67 (24.57–26.75) 0–4: 18.68 5–9: 31.59 10–15: 39.06 15–19: 14.70 | 27.23 | 24.39
Alabama, 2000–2017 (52) | <19 | Hospital-based (comprises 87% of all children diagnosed with T1D in Alabama) | Clinical diagnosis | [underlined: Age (years)] <19: 16.7 <1: 1.6 1–4: 15.1 5–9: 22.6 10–14: 22.6 15–19: 6.3 | 13.7 | 14.8
SEARCH Registry, 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | [underlined: Age (years)] 2002–2003: <20: 19.5 2017–2018: <20: 22.2 0–4: 14.4 5–9: 26.2 10–14: 33.2 15–19: 14.6 | [underlined: All ages] 2002–2003: 19.8 2017–2018: 23.8 | [underlined: All ages] 2002–2003: 19.2 2017–2018: 20.6
Southern California, 2016–2021 (54) | <20 | Kaiser Permanente Southern California | Clinical diagnosis | [underlined: Age (years)] 2016–2019: <20: 18.1 0–9: 14.7 10–19: 20.9 2020–2021: <20: 21.1 0–9: 17.0 10–19: 24.0 | [underlined: All ages] 2016–2019: 18.5 2020–2021: 21.8 | [underlined: All ages] 2016–2019: 17.7 2020–2021: 20.3
Non-Hispanic White
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | 28.88
Alabama, 2000–2017 (52) | <19 | Hospital-based (comprises 87% of all children diagnosed with T1D in Alabama) | Clinical diagnosis | 17.0
SEARCH Registry, 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | 2002–2003: 23.9 2017–2018: 26.4
Southern California, 2016–2021 (54) | <20 | Kaiser Permanente Southern California | Clinical diagnosis | 2016–2019: 27.31 2020–2021: 29.78
Non-Hispanic Black
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | 19.07
Alabama, 2000–2017 (52) | <19 | Hospital-based (comprises 87% of all children diagnosed with T1D in Alabama) | Clinical diagnosis | 12.4
SEARCH Registry, 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | 2002–2003: 14.7 2017–2018: 22.1
Southern California, 2016–2021 (54) | <20 | Kaiser Permanente Southern California | Clinical diagnosis | 2016–2019: 27.18 2020–2021: 34.90
Hispanic
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | 14.64
SEARCH Registry, 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | 2002–2003: 13.7 2017–2018: 17.7
Southern California, 2016–2021 (54) | <20 | Kaiser Permanente Southern California | Clinical diagnosis | 2016–2019: 15.4 2020–2021: 18.6
Asian or Pacific Islander
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | 5.57
SEARCH Registry 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | 2002–2003: 7.9 2017–2018: 9.4
Southern California, 2016–2021 (54) | <20 | Kaiser Permanente Southern California | Clinical diagnosis | 2016–2019: 8.0 2020–2021: 12.8
American Indian/Alaska Native
Utah, 1998–2015 (53) | 0–19 | Utah Population Database and medical records from two healthcare systems | Clinical diagnosis | 11.1
SEARCH Registry, 2002–2003 and 2017–2018* (62) | <20 | SEARCH study registry | Clinical diagnosis | 2002–2003: 6.6 2017–2018: 7.8

CI, confidence interval; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes.

* The SEARCH registry includes Colorado, Ohio, South Carolina, and Washington state, as well as members of a single large health plan in southern California (Kaiser Permanente) and selected American Indian reservations in Arizona and New Mexico

SOURCE: References are listed within the table.

TABLE 4.

Reported Incidence of Type 1 Diabetes in Youth Age <20 Years in European Countries

COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | INCIDENCE CASES/100,000/YEAR (95% CI)
COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | Overall | Males | Females
Spain / Navarre, 1977–2016 (123) | 0–14 | The five hospitals in Navarre were used as a primary source, and the Navarre Diabetes Association (ANADI) and the primary health care system were used as secondary sources of cases. | Clinical diagnosis | 15.0 (13.8–16.3) | 15.1 (13.5–16.7) | 14.8 (13.1–16.7)
Montenegro, 1991–2020 (124) | 0–14 | Diabetes Registry of Montenegro | Clinical diagnosis | 15.6 (14.4–46.9) | 16.4 (14.6–18.3) | 14.8 (13.0–16.6)
Germany / Saxony, 1999 and 2019 (125) | 0–14 | Childhood Diabetes Registry of Saxony | Clinical diagnosis | 1999: 17.1 2019: 24.7
Germany / North Rhine- Westphalia, 2002–2022 (126) | 0–19 | German Diabetes Center Düsseldorf | Clinical diagnosis | 23.7 (23.3–24.0) | 25.3 (24.8–25.8) | 22.0 (21.5–22.5)
Finland, 2003–2018 (76) | <15 | Finnish Pediatric Diabetes Register | Clinical diagnosis | 2003–2018: 54.9 (53.7–56.1) 2003–2006: 57.9 (55.4–60.4) 2007–2010: 56.0 (53.6–58.6) 2011–2014: 53.4 (51.1–55.9) 2015–2018: 52.2 (49.8–54.6) | 2003–2018: 60.3 (58.5–62.1) 2003–2006: 63.5 (59.9–67.2) 2007–2010: 61.2 (57.6–64.9) 2011–2014: 58.8 (55.3–62.4) 2015–2018: 57.7 (47.9–60.0) | 2003–2018: 49.2 (47.6–50.9) 2003–2006: 52.0 (48.7–55.5) 2007–2010: 50.7 (47.4–54.1) 2011–2014: 47.9 (44.7–51.2) 2015–2018: 46.3 (43.2–49.7)
Spain / Biscay, 2003–2022 (127) | <15 | Registry of incident diabetes | Clinical diagnosis | 13.0 (11.4–13.9) | 13.6 | 12.3
Slovakia, 2004–2008 and 2014–2017 (128) | <19 | The Children Diabetes Center | Clinical diagnosis | | 2004–2008: 10.7 2014–2017: 13.4 | 2004–2008: 14.5 2014–2017: 15.1
Italy / Marche and Piedmont, 2004–2021 (129) | 0–14 | Population-based T1D incidence registry | Clinical diagnosis | 2004–2019: 18.3 (16.3–20.2) 2020: 21.6 (18.3–25.3) 2021: 26.7 (23.0–30.9)
Serbia, 2006–2017 (112) | <20 | Population-based diabetes register | Clinical diagnosis | [underlined: Age (years)] <5: 8.6 5–9: 17.0 10–14: 21.1 15–19: 10.4
U.K. / Scotland, 2006–2019 (42) | <15 | Scottish Care Information – Diabetes Collaboration | Clinical diagnosis and prescriptions | | 39.9 | 39.7
Serbia, 2007–2017 (130) | ≤19 | All 15 regional secondary or tertiary healthcare centers caring for individuals with T1D | Clinical diagnosis | [underlined: Age (years)] 0–4: 9.8 5–9: 16.6 10–14: 17.1 15–19: 4.2 | [underlined: Age (years)] 0–4: 10.0 5–9: 15.8 10–14: 17.98 15–19: 4.84 | [underlined: Age (years)] 0–4: 9.6 5–9: 17.5 10–14: 16.1 15–19: 3.4
Turkey / Malatya, 2007–2019 (131) | <18 | Retrospective review of pediatric diabetes clinic records | Clinical diagnosis | 13.1 (11.8–14.4) | 12.4 (10.7–14.2) | 13.8 (11.9–15.8)
U.K. / Wales, 2008–2018 (45) | ≤14 | Primary and secondary care throughout Wales available in the SAIL Databank | Clinical diagnosis | 33.6 (28.0–39.6)
Spain / Navarre, 2009–2016 (123) | <15 | Primary data sources were all public and private hospitals in the region of Navarre. Secondary data sources were: (1.) primary care centers, through the Clinical Planning and Management Service; (2.) the electronic clinical histories shared between primary and specialized care; and (3.) the Navarre Diabetes Association (ANADI). | Clinical diagnosis and biomarkers | | [underlined: Age (years)] 0–4: 14.3 (8.7–22.1) 5–9: 23.1 (15.8–32.6) 10–14: 37.2 (27.4–49.3) | [underlined: Age (years)] 0–4: 14.4 (8.6–22.5) 5–9: 21.1 (14–30.6) 10–14: 19.4 (12.4–29)
Austria, 2009–2017 (104) | <15 | Austrian Diabetes Incidence Study | Clinical diagnosis and prescriptions | 2009: 18.4 2010: 18.4 2011: 21.5 2012: 23.1 2013: 19.5 2014: 22.7 2015: 19.7 2016: 22.8 2017: 22.5 | 2009: 19.4 2010: 18.8 2011: 23.7 2012: 24.7 2013: 21.4 2014: 24.6 2015: 19.1 2016: 23.5 2017: 23.2 | 2009: 17.4 2010: 17.9 2011: 19.1 2012: 21.4 2013: 17.4 2014: 20.6 2015: 20.5 2016: 22.2 2017: 21.7
Turkey / Elazig, 2009–2019 (99) | <15 | Retrospective review of pediatric diabetes clinic records | Clinical diagnosis | 16.7 (14.6–19.0) | 16.8 (13.9–20.1) | 16.5 (13.6–19.9)
Spain / Navarre, 2009–2020 (40) | <15 | Navarre Type 1 Diabetes Population Registry | Clinical diagnosis and biomarkers | 8.1 (7.5–8.8) | [underlined: Age (years)] 0–4: 13.9 (9.2–20.0) 5–9: 22.3 (16.4–29.6) 10–14: 34.3 (26.7–43.5) | [underlined: Age (years)] 0–4: 13.0 (8.4–19.2) 5–9: 18.9 (13.4–26.0) 10–14: 20.9 (14.9–28.4)
Ireland, 2011–2016 (44) | 0–14 | National pharmacy claims data | Prescriptions | 31.7 (28.2–35.2)
Spain / Asturias, 2011–2020 (41) | <15 | Pancreatic autoimmunity registry of the Hospital Universitario Central de Asturias districts of Asturias | Clinical diagnosis and prescriptions and biomarkers | [underlined: Age (years)] <15: 7.8 (7.3–8.4) 0–4: 10.6 (7.5–14.6) 5–9: 20.8 (16.6–25.8) 10–14: 26.6 (21.67–32.2) | [underlined: Age (years)] <15: 8.7 (7.9–9.6) 0–4: 10.0 (5.9–15.7) 5–9: 20.7 (15.0−27.8) 10–14: 31.2 (23.9−40.0) | [underlined: Age (years)] <15: 7.01 (6.3–7.8) 0–4: 11.3 (6.8−17.6) 5–9: 21.0 (15.2−28.4) 10–14: 21.7 (15.6−29.5)
Germany, 2011–2021 (97) | 0.5–<18 | The German Diabetes Prospective Follow-up Registry and the Federal Statistical Office | Clinical diagnosis | 2011–2019: 19.8 (19.5–20.0) 2020: 24.9 (24.0–25.7) 2021: 27.0 (26.1–27.9)
Italy / Abruzzo region, 2012–2017 (103) | <18 | The primary source was territorial pharmaceutical insulin prescriptions (2012–2017) and medical records. | Clinical record review and prescriptions | 2012: 15.6 (11.0–22.0) 2013: 16.4 (11.7–23.0) 2014: 11.6 (7.8–17.4) 2015: 14.2 (9.8–20.4) 2016: 16.2 (11.5–22.7) 2017: 12.2 (8.3–18.1)
U.K. / North East England and North Cumbria, 2012–2020 (132) | 0–14 | North East and North Cumbria Young Persons diabetes register | Clinical diagnosis | 21.3 (19.9–22.7) | 22.2 (20.3–24.2) | 20.1 (18.3–22.0)
Spain / Community of Madrid, 2014–2016 (133) | <15 | T1DM register of the Community of Madrid | Clinical diagnosis | [underlined: Age (years)] <15: 20.0 (18.4–21.6) 0–4: 11.3 (9.2–13.4) 5–9: 22.8 (20.0–25.6) 10–14: 25.5 (22.3–28.6) | [underlined: Age (years)] <15: 21.5 (19–23.8) 0–4: 10.8 (7.9–13.6) 5–9: 23.2 (18.9–27.4) 10–14: 30.4 (25.6–35.2) | [underlined: Age (years)] <15: 19.3 (17.1–21.6) 0–4: 12.2 (9.1–15.4) 5–9: 25.1 (20.8–29.3) 10–14: 20.1 (16.1–24.1)
Ireland, 2014–2018 (95) | <15 | Irish Childhood Diabetes National Register (ICDNR) | Clinical diagnosis | 2014: 28.0 2015: 29.6 2016: 30.9 2017: 27.0 2018: 27.1
Italy / Emilia-Romagna region, 2015–2018 (96) | 0–14 | All regional centers of pediatric diabetology | Clinical diagnosis | 15.4
Italy / Veneto Region, 2015–2020 (65) | 0–18 | Regional electronic health archives | Clinical diagnosis | [underlined: Age (years)] 0–18: 19.7 (18.4–21.0) 0–4: 12.1 (9.9–14.2) 5–9: 22.2 (19.5–24.9) 10–14: 22.2 (19.5–24.9) 15–18: 21.5 (18.5–24.5) | 20.9 (19.0–22.8) | 18.5 (16.6–20.3)
Romania, 2015–2020 (134) | 0–14 | Romanian National Diabetes Register | Clinical diagnosis | 2015: 11.0 2016: 12.3 2017: 11.5 2018: 11.2 2019: 11.4 2020: 13.3 | 2015: 11.3 2016: 11.6 2017: 10.6 2018: 11.1 2019: 11.7 2020: 13.5 | 2015: 10.8 2016: 13.2 2017: 12.4 2018: 11.3 2019: 10.9 2020: 13.0
Serbia / Province of Vojvodina, 2017–2018 (135) | 0–19 | Four regional centers in Vojvodina | Clinical diagnosis | 2017: 10.6 2018: 13.2
Bosnia and Herzegovina / Republic of Srpska, 2017–2022 (78) | 0–14 | | Clinical diagnosis | 2017: 12.9 2018: 15.5 2019: 22.4 2020: 28.7 2021: 17.6 2022: 17.0 [underlined: 2017–2022] Age (years): 0–4: 12.5 5–9: 18.4 10–14: 26.1 | 2017: 16.8 2018: 15.7 2019: 17.0 2020: 26.8 2021: 23.3 2022: 17.2 | 2017: 8.8 2018: 15.3 2019: 28.1 2020: 30.8 2021: 11.6 2022: 16.8
Germany / Bavaria, 2018–2021 (136) | <12 | Health insurance claims data | Prescriptions | 2018–2019: 19.5 (17.8–21.4) 2020–2021: 29.9 (27.7–32.2)
Italy / Calabria, 2019–2021 (77) | 0–14 | Electronic medical record review of children and adolescents diagnosed with diabetes at any Pediatric Diabetes Center belonging to the Rete Diabetologica Calabrese | Clinical diagnosis | 20.6 (17.6–24.1) [underlined: Age (years)] 0–4: 15.7 (11.1–21.6) 5–9: 24.1 (18.6–30.8) 10–14: 21.6 (16.5–27.7) | 17.9 (14.1–22.6) | 23.4 (18.6–28.5)
Italy / Sardinia, 2019–2022 (74) | 0–14 | All pediatric diabetology clinics in Sardinia | Clinical diagnosis | 73.9 (66.8–79.6) 2019: 63.5 (52.4–76.3) 2020: 70.7 (58.8–84.3) 2021: 85.8 (72.5–100.8) 2022: 76.3 (63.6–90.8) | 81.6 (72.50–91.5) | 65.8 (57.4–75.1)
Turkey / Diyarbakır city, 2020 (100) | <19 | Retrospective review of medical records from three tertiary pediatric endocrinology centers | Clinical diagnosis | 8.0 | 6.3 | 9.8
Germany, 2020–2021 (137) | 0.5–<18 | German Diabetes Prospective Follow-up Registry | Clinical diagnosis | [underlined: Age (years)] 0.5–<18: 24.4 (23.6–25.2) <6: 18.6 (17.5–19.8) 6–11: 32.7 (31.2–34.3) 12–17: 23.5 (22.2–24.8) | 26.6 (25.5–27.8) | 21.9 (20.9–23.0)

International data are organized by International Diabetes Federation (IDF)-defined regions. CI, confidence interval; T1D/T1DM, type 1 diabetes mellitus.

SOURCE: References are listed within the table.

TABLE 5.

Reported Incidence of Type 1 Diabetes in Youth Age <20 Years, Other Regions

COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | INCIDENCE CASES/100,000/YEAR (95% CI)
COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | Overall | Males | Females
Africa
Mali, 2007–2016 (69) | <25 | Prospective program register | Clinical diagnosis | 2007: 0.12 (0.06–0.22) 2016: 0.74 (0.59–0.91)
Tanzania, 2010–2016 (68) | <15 | Retrospective review of medical records | Clinical diagnosis | Dar es Salaam: 1.8 Kilimanjaro: 1.8 Zanzibar: 1.9
Burkina Faso, 2013–2022 (70) | <25 | Prospective program register | Clinical diagnosis | 2013: 0.08 (0.07–0.33) 2022: 0.34 (0.26–0.45) | 2013: 0.05 (0.01–0.16) 2022: 0.25 (0.16–0.39) | 2013: 0.10 (0.04–0.23) 2022: 0.44 (0.31–0.62)
Eritrea, 2019 (81) | <25 | Medical records | Clinical diagnosis | 22.8 (20.9–24.8) | 25.9 (23.1–28.9) | 19.5 (17.1–22.2)
Middle East and North Africa
Iran / Isfahan province, 2007–2019 (84) | <20 | Retrospective | Prescription based | 2015–2016: 18.6 (11.5–25.7) 2016–2017: 14.1 (7.9–20.3) 2017–2018: 16.3 (9.7–23.0) 2018–2019: 14.5 (8.2–20.7) | 2015–2016: 15.2 (8.8–21.6) 2016–2017: 14.4 (8.2–20.7) 2017–2018: 18.2 (11.2–25.2) 2018–2019: 13.9 (7.8–20.1) | 2015–2016: 18.6 (11.5–25.7) 2016–2017: 13.9 (7.8–20.0) 2017–2018: 14.7 (8.4–20.9) 2018–2019: 15.2 (8.8–21.6)
Libya / West, South, and Tripoli regions, 2009–2018 (80) | <15 | Review of hospital records | Clinical diagnosis | 2009–2013: 29.3 (26.6–32.2) 2014–2018: 31.7 (29.2–34.2) | 2009–2013: 28.1 (24.5–32.2) 2014–2018: 31.0 (27.7–34.7) | 2009–2013: 30.6 (26.7–34.9) 2014–2018: 32.4 (28.9–36.3)
Qatar, 2012–2016 (82) | <15 | National pediatric diabetes center register | Medical record review | 2012–2016: 28.4 2012: 25.9 2013: 26.1 2014: 24.7 2015: 33.5 2016: 31.8
Northwest Algeria / Tlemcen, 2015–2018 (79) | <15 | Hospital registers, medical records, and Algerian social security system | Clinical diagnosis | 38.5 (35.2–41.8) | 40.5 (38.2–42.9) | 36.5 (34.2–38.8)
Qatar, 2018–2020 (72,83) | <19 | Prospective pediatric diabetes center cohort | Clinical diagnosis plus biomarkers | 38.1 (32.5–44.3)
Western Pacific Region
New Zealand / Canterbury, 1970–2019 (91) | <15 | Prospective diabetes register for children diagnosed with T1DM after 1982 | Clinical diagnosis | Lowest, 1972: 3.2 Highest, 2019: 36.1
New Zealand / Auckland, 1977–2019 (90) | <15 | Prospective regional database (1990–2019) and retrospective review of medical and lab records | Clinical diagnosis | Lowest, 1978: 7.1 Highest, 2015: 25.0
Japan / Oita Prefecture, 1999–2021 (105) | <15 | Retrospective review of hospital records, interviews with pediatricians, and national health insurance beneficiaries database | Clinical diagnosis plus biomarkers | 3.9
Australia / Western Australia, 2001–2022 (88) | <15 | Regional register | Clinical diagnosis | 22.9 (22.0–23.9) | 23.5 (22.2–24.8) | 22.3 (21.0–23.7)
Australia, 2002–2017 (87) | <15 | National register | Clinical diagnosis | 25.0 (24.6–25.4) | 25.3 (24.8– 25.9) | 23.0 (22.4– 23.7)
South Korea, 2008–2016 (73) | <15 | National claims data | Clinical diagnosis plus prescription based | 2008: 3.7 (3.3–4.1) 2016: 4.8 (4.3–5.3) | 2008: 3.1 (2.6–3.6) 2016: 4.9 (4.2–5.7) | 2008: 4.4 (3.8–5.1) 2016: 4.6 (4.0–5.4)
Hong Kong, 2008–2017 (86) | <18 | Hospital register | Clinical diagnosis plus biomarkers | 4.3 (4.0–4.7)
China / Henan Province, 2017–2020 (85) | <15 | Retrospective review of hospital register | Clinical diagnosis | 2.2 (2.0–2.4) | 1.9 (1.7–2.2) | 2.5 (2.2–2.9)
New Zealand, 2020–2021 (89) | <15 | Review of medical records from pediatric diabetes centers | Clinical diagnosis | 23
North America and Caribbean
Mexico, 2000–2018 (92) | <20 | National public insurance register | Clinical diagnosis | 2015: 3.0 (2.7–3.2) 2016: 3.1 (2.8–3.3) 2017: 3.3 (3.0–3.5) 2018: 2.8 (2.6–3.1)
Dominican Republic, 2010–2019 (93) | <15 | Retrospective review of medical records from four national pediatric endocrinology clinics | Clinical diagnosis | 2015: 3.3 (3.8–5.4) 2016: 3.7 (3.0–4.4) 2017: 4.5 (3.8–5.4) 2018: 4.2 (3.5–5.0) 2019: 4.2 (3.5–5.0) | 2015: 2.2 (1.5–3.1) 2016: 3.2 (2.3–4.2) 2017: 3.7 (2.8–4.8) 2018: 3.7 (2.8–4.8) 2019: 3.4 (2.5–4.5) | 2015: 4.4 (3.4–5.6) 2016: 4.2 (3.2–5.4) 2017: 5.3 (4.2–6.7) 2018: 4.7 (3.7–6.0) 2019: 5.0 (3.9–6.3)
South and Central America
Chile, 2006–2021 (94) | <20 | Nationwide registry | Clinical diagnosis | 12.7

“Other regions” refers to countries outside of the United States (see Table 3) and Europe (see Table 4). International data are organized by International Diabetes Federation (IDF)-defined regions. CI, confidence interval; T1D, type 1 diabetes.

SOURCE: References are listed within the table.

TABLE 6.

Prevalence of Type 1 Diabetes Among Adults Age ≥20 Years, NHIS, U.S., 2019–2023

CHARACTERISTICS | PREVALENCE OF TYPE 1 DIABETES*
CHARACTERISTICS | Weighted N | PERCENT (STANDARD ERROR)
Total | 944,786 | 0.39 (0.02)
Age (years)
20–39 | 379,970 | 0.44 (0.04)
40–59 | 300,617 | 0.37 (0.03)
≥60 | 264,198 | 0.34 (0.03)
Sex
Men | 474,935 | 0.40 (0.03)
Women | 469,851 | 0.37 (0.03)
Race/ethnicity
Non-Hispanic White | 696,787 | 0.45 (0.02)
Non-Hispanic Black | 99,006 | 0.34 (0.06)
Hispanic | 89,453 | 0.22 (0.04)
Non-Hispanic Asian | 33,620 | 0.23 (0.08)^1^
Non-Hispanic American Indian/Alaska Native | 20,272 | 0.60 (0.25)^2^

* In the NHIS, type 1 diabetes is defined as self-report of type 1 diabetes, continuous insulin use within 1 year of diagnosis, and current insulin use.

^1^ Relative standard error 30%–<40%

^2^ Relative standard error 40%–<50%

SOURCE: National Health Interview Surveys (NHIS) 2019–2023

TABLE 7.

Prevalence of Type 1 Diabetes Among Adults Age ≥20 Years, NHANES, U.S., 2017–2023

CHARACTERISTICS | PREVALENCE OF TYPE 1 DIABETES*
CHARACTERISTICS | Weighted N | PERCENT (STANDARD ERROR)
Total | 1,602,585 | 0.66 (0.09)
Age (years)
20–39 | 513,779 | 0.59 (0.17)
40–59 | 584,436 | 0.71 (0.17)
≥60 | 504,369 | 0.69 (0.12)
Sex
Men | 861,584 | 0.74 (0.12)
Women | 741,001 | 0.59 (0.15)
Race/ethnicity
Non-Hispanic White | 1,172,703 | 0.79 (0.12)
Non-Hispanic Black | 190,797 | 0.70 (0.18)
Hispanic | 138,918 | 0.35 (0.10)
Non-Hispanic Asian | 26,585 | ^1^

* In the NHANES, type 1 diabetes is defined as self-report of diabetes, current insulin use only (no oral agents), and started insulin within 1 year of diagnosis (based on Mosslemi et al. (47)).

^1^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys (NHANES) 2017–2023

TABLE 8.

Prevalence of Type 1 Diabetes in Adults in European Countries

COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | PREVALENCE PER 100 PER YEAR (95% CI)
COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | Overall | Males | Females
Denmark, 1999−2016 (109) | 0−99 | National Diabetes Register | Clinical and prescription based | 2016: 0.50 | 0.50 | 0.40
U.K. / Wales, 2008−2018 (45) | 0−60 | Primary and secondary care throughout Wales available in the SAIL Databank | Clinical diagnosis | [underlined: Age (years)] 0−60: 0.32 (0.31−0.32) 15−29: 0.52 (0.50−0.55) 30−44: 0.45 (0.43−0.47) 45−60: 0.33 (0.31−0.35) | 0.35 (0.34−0.36) | 0.28 (0.27−0.29)
Ireland, 2011−2016 (44) | All ages | National pharmacy claims data | Prescription based | 0.42 (0.42−0.43) [underlined: Age (years)] 15−24: 0.38 (0.36−0.39) 25−34: 0.36 (0.34−0.37) 35−44: 0.38 (0.37−0.39) 45−54: 0.46 (0.45−0.48) 55−64: 0.57 (0.55−0.59) 65−74: 0.72 (0.69−0.75) ≥75: 0.74 (0.71−0.77) | 0.46 | 0.37
Greece, 2014−2015 (108) | ≥15 | The National Organization for Health Care Services Provision | Clinical and prescription based | 0.27 | [underlined: Age (years)] 15−24: 0.20 25−34: 0.20 35−44: 0.27 45−54: 0.30 55−64: 0.33 65−74: 0.41 ≥75: 0.48 | [underlined: Age (years)] 15−24: 0.19 25−34: 0.17 35−44: 0.23 45−54: 0.23 55−64: 0.23 65−74: 0.29 ≥75: 0.38

CI, confidence interval.

SOURCE: References are listed within the table.

TABLE 9.

Incidence of Type 1 Diabetes in Adults in the U.S. and Selected Non-U.S. Countries

COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | INCIDENCE CASES/100,000/YEAR (95% CI)
COUNTRY / REGION, YEARS OF DATA COLLECTION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | Overall | Males | Females
United States
California, 2017 (38) | 20–45 | Kaiser Permanente, California Healthcare System Database | Clinical diagnosis, prescription data, and/or biomarkers | 30.1 (23.5−36.8) | 32.5 (22.2−42.8) | 27.2 (21.0−34.5)
Europe
United Kingdom, 2000–2002 and 2017−2019 (111) | 15−29 | Clinical Practice Research Datalink | Clinical diagnosis | 2000–2002: 5.3 2017–2019: 5.9 | 2000–2002: 5.3 2017–2019: 5.9
Sweden, 2001–2020 (114) | ≥18 | National diabetes, patient, and prescribed drugs registers | Clinical diagnosis | 18.8 | 22.2 | 15.3
U.K. / Scotland, 2006–2019 (42) | ≥15 | Scottish Care Information— Diabetes Collaboration | Prescriptions | Excluding possible diabetes*: 4.4 | [underlined: Age (years)] 15−29: 32.0 30−49: 21.3 ≥50: 10.0 | [underlined: Age (years)] 15−29: 21.7 30−49: 12.7 ≥50: 8.3
Serbia, 2006−2017 (112) | 20−29 | Population-based Serbian Diabetes Registry | Glucose and symptoms | [underlined: Age (years)] 20−24: 8.36 25−29: 8.22
U.K. / Wales, 2008–2018 (45) | 15−60 | Primary and secondary care throughout Wales available in the SAIL Databank | Clinical diagnosis | [underlined: Age (years)] 15−29: 26.87 (22.32−31.83) 30−44: 13.15 (10.02−16.70) 45−60: 6.49 (4.39−8.98)
Spain / Asturias, 2009−2020 (41) | ≥15 | Pancreatic autoimmunity registry (whole of region) | Clinical diagnosis | [underlined: Age (years)] ≥15: 7.82 (7.29–8.37) 15−29: 11.11 (9.34−13.12) 30−39: 8.90 (7.42−10.59) 40−60: 5.94 (5.14−6.82) >60: 3.87 (3.23−4.60) | [underlined: Age (years)] 15−29: 13.65 (10.94–16.84) 30−39: 11.14 (8.83–13.87) 40−60: 6.07 (4.93–7.39) >60: 3.14 (2.28–4.21) | [underlined: Age (years)] 15−29: 8.47 (6.32–11.0) 30−39: 6.63 (4.82–8.81) 40−60: 5.81 (4.72–7.81) >60: 4.42 (3.52–5.47)
Spain / Navarre, 2011–2020 (40) | ≥15 | Type 1 Diabetes Population Registry | Clinical diagnosis and biomarkers | 8.1 (7.5−8.8) | [underlined: Age (years)] ≥15: 10.0 (9.0−11.0) 15–29: 17.4 (14.2−21.0) 30–44: 10.3 (8.3−12.6) ≥45: 2.1 (1.5−3.0) | [underlined: Age (years)] ≥15: 6.3 (5.5−7.1) 15–29: 9.1 (6.9−11.9) 30–44: 5.6 (4.1−7.4) ≥45: 2.0 (1.4−2.8)
Ireland, 2011–2016 (44) | ≥15 | National pharmacy claims data | Prescriptions | [underlined: Age (years)] ≥15: 32.07 (30.46−33.68) 15−24: 26.89 (22.66−31.12) 25−34: 29.88 (25.70−34.05) 35−44: 31.20 (27.19−35.20) 45−54: 23.96 (20.13−27.79) 55−64: 29.86 (25.12−34.61) 65−74: 41.23 (34.72−47.74) ≥75: 54.15 (45.28−63.03) | 34.83 | 28.29
Denmark, 2015–2021 (46) | All ages | National Patient and Prescription Registers | Clinical diagnosis, prescriptions | [underlined: 2015−2019] Jan−Mar: 28.4 (26.3−30.6) Apr−Jun: 23.6 (21.7−25.6) Jul−Sep: 25.5 (23.5−27.6) Oct−Dec: 26.5 (24.5−28.6) [underlined: 2021] Jan−Mar: 28.5 (24.1−33.7) Apr−Jun: 31.6 (27.0−37.0) Jul−Sep: 30.5 (26.0−35.8) Oct−Dec: 31.0 (26.4−36.4)
Italy / Piedmont, 2017−2022 (113) | 15−29 | Regional registry of diabetes and the Piedmont DM1 Surveillance Register | Clinical diagnosis | 2017−2019: 10.44 2020−2022: 12.52
Western Pacific Region
China, 2007–2021 (110) | All ages | Beijing Municipal Health Commission Information Center | Clinical diagnosis | [underlined: Year and age (years)] 2015: 15−29: 3.25 ≥30: 3.82 2016: 15−29: 4.05 ≥30: 4.10 2017: 15−29: 3.54 ≥30: 4.47 2018: 15−29: 3.49 ≥30: 4.71
Japan, 2014–2017 (43) | ≥20 | The National Database of Health Insurance Claims and Specific Health Check-ups of Japan (NDB) | Clinical diagnosis | | [underlined: Age (years)] 20−39: 5.57 40−59: 5.70 ≥60: 3.48 | [underlined: Age (years)] 20−39: 4.83 40−59: 4.99 ≥60: 3.31

International data are organized by International Diabetes Federation (IDF)-defined regions. CI, confidence interval, DM1, diabetes mellitus, type 1.

* Possible type 1 diabetes was defined as cases with a clinical record of type 2 diabetes with an insulin prescription within a year of diabetes diagnosis but no record of prescription of treatments for diabetes other than metformin.

SOURCE: References are listed within the table.

TABLE 10.

Incidence of Type 1 Diabetes in Youth and Young Adults Before and After the COVID-19 Pandemic

COUNTRY / REGION (REF.) | AGE (YEARS) | STUDY METHODS | TYPE 1 DIABETES DEFINITION | PRE-COVID-19 PERIOD | PRE-COVID-19 INCIDENCE CASES/100,000 (95% CI) | POST-COVID-19 PERIOD | POST-COVID-19 INCIDENCE CASES/100,000 (95% CI)
United States / California (54) | ≤19 | Data from a managed care organization (Kaiser Permanente Southern California) | Two or more diabetes diagnosis codes or identified as having diabetes in the SEARCH registry | 2016–2019 | 18.09 | 2020–2021 | 21.13
Denmark (46) | <30 | National Diabetes Registry | Clinical diagnosis | 2015–2019 | Q1: 28.4 (26.3−30.6) Q2: 23.6 (21.7−25.6) Q3: 25.5 (23.5− 27.6) Q4: 26.5 (24.5−28.6) | 2020 and 2021 | [underlined: 2020] Q1: 28.8 (24.4−33.9) Q2: 23.0 (19.1−27.7) Q3: 28.5 (24.2−33.6) Q4: 28.8 (24.4−33.9) [underlined: 2021] Q1: 28.5 (24.1−33.7) Q2: 31.6 (27.0−37.0) Q3: 30.5 (26.0−35.8) Q4: 31.0 (26.4−36.4)
Japan / Oita Prefecture (105) | <15 | Retrospective review of hospital records, interviews with pediatricians, and national health insurance beneficiaries database | Clinical diagnosis plus biomarkers | 1999–2018 | Annual percentage change: +5.3% | 1999–2021 | Annual percentage change: +4.7%
China / Hubei Province (117) | <15 | Retrospective review of single-center regional hospital records | Clinical diagnosis | 2017–2019 | 2017: 2.4 2018: 2.8 2019: 3.0 | 2020–2022 | 2020: 2.0 2021: 4.7 2022: 2.9
Thailand / Chiang Mai, Chiang Rai, Lamphun, and Mae Hong Son Provinces (118) | <15 | Prospective program register | Clinical diagnosis | 2017–2019 | 2017: 2.3 (1.0–3.6) 2018: 1.4 (0.4–2.5) 2019: 2.6 (1.2–4.1) Overall average: 2.1 | 2020–2022 | 2020: 1.8 (0.6–3.0) 2021: 2.2 (0.9–3.5) 2022: 3.1 (1.5–4.7) Overall average: 2.4
Australia / Western Australia (88) | <15 | Regional register | Clinical diagnosis | 2017–January 2020 | 22.7 (21.7–23.8) | February 2020–December 2022 February 2020–January 2022 (low COVID case period) February 2022–December 2022 (high COVID case period) | 24.0 (21.6–26.6) 24.9 (22.0–28.2) 21.9 (18.0–26.6)
Chile (94) | <20 | Nationwide registry (mandatory reporting of T1DM) | Clinical diagnosis | 2006–2019 | 11.7 | 2020–2021 | 20.2

CI, confidence interval; COVID-19, coronavirus disease of 2019; SEARCH, SEARCH for Diabetes in Youth study; T1DM, type 1 diabetes mellitus.

SOURCE: References are listed within the table.