# Infections Associated With Diabetes

## Summary

Evidence from centuries of clinical practice supports the relationship between diabetes and infections. Possible mechanisms include the effect of hyperglycemia on the immune system, increased risk of local tissue ischemia, neuropathy, and the association of diabetes with other comorbidities, such as obesity and heart failure, that independently increase the risk of infection. Individuals with diabetes are more likely to develop certain infections compared to those without diabetes, including urinary tract infections (such as asymptomatic bacteriuria, pyelonephritis, renal and perinephric abscess), respiratory tract infections, sepsis, lower extremity infections, deep subcutaneous tissue infections, and tuberculosis. In addition, several rare but serious infections occur almost exclusively in people with diabetes, including necrotizing otitis externa, rhinocerebral mucormycosis, emphysematous pyelonephritis, and Fournier’s gangrene. Though it remains unclear whether diabetes is associated with a higher risk of acquiring COVID-19, evidence suggests diabetes is associated with significantly elevated risk of severe and fatal complications from the infection.

In the United States in 1999–2023, the age-standardized percentage of deaths with any infection ranged from 2.3% to 16.8% in persons with diabetes compared with 3.5% to 14.6% in persons without diabetes, with respiratory tract infections accounting for the highest percentage of deaths in both groups. In addition, during 1999–2021, the age-standardized percent of hospital discharges listing any infection ranged from 19.5% to 34.9% in persons with diabetes compared with 12.1% to 23.4% in persons without diabetes. Skin and connective tissue infections were the most common for individuals with diabetes, while respiratory tract infections accounted for the highest percentage of hospital discharges in those without diabetes. Individuals with diabetes who develop infections face higher rates of hospital admission, longer stays, and more complications, which in turn increase healthcare costs. This article summarizes the body of evidence on the relationship between diabetes and infectious disease risks and outcomes. It also outlines implementation strategies to facilitate adoption of evidence-based care for diabetes-related infections.

## Introduction

The relationship between diabetes and infections, such as erysipelas, pneumonia, and tuberculosis (TB), has been documented in clinical practice for centuries (Table 1) (1,2). Historically, diabetes contributed considerably to morbidity and mortality, particularly prior to the advent of insulin and antibiotics (3,4). Recent studies quantifying the burden of infection-related complications in people with diabetes have shown a significant risk of hospitalization for infections, particularly foot infections, respiratory infections, urinary tract infections (UTIs), sepsis, and postoperative infections (3). Individuals with diabetes who develop infections also face higher rates of hospital admission, longer stays, and more complications, which in turn increase healthcare costs (5). In the post-COVID (coronavirus disease of 2019) pandemic world, it is important to note that although diabetes does not increase the risk of contracting COVID-19, it significantly elevates the risk of severe and fatal complications from the infection (3). In addition, certain rare and sometimes fatal infections, known as signal infections, occur more commonly and are pathognomonic for diabetes, including emphysematous pyelonephritis (EPN), necrotizing otitis externa (NOE), mucormycosis, and Fournier’s gangrene (5).

Despite advances in understanding and managing infections in diabetes, large cohort studies show that the risk of hospitalization and death from infections attributable to diabetes remains substantial. A 2024 Swedish population-based study demonstrated significantly higher rates of hospital admissions and mortality among individuals with diabetes compared to those without (6), while global analyses confirmed that infection contributes disproportionately to mortality in type 2 diabetes. Respiratory tract infections, followed by skin and connective tissue infections, remain the most common infections diagnosed in people with diabetes (6,7,8,9). Evidence suggests that diabetes disrupts host-related factors, such as the consolidation and integrity of the mucosa and skin, and targets the immune system at multiple levels, impairing both innate and adaptive immunity by reducing the function of complement, neutrophils, NK cells, and T cells (10). This dysregulation weakens the immune system, making individuals with diabetes more susceptible to severe infections (10).

This article reviews the burden of infectious diseases, mechanisms that increase susceptibility to infections, and strategies for evidence-based care of infections in persons with diabetes; this content updates the Diabetes in America, 3rd edition, chapter Infections Associated With Diabetes (11). The types of infections described in this article are summarized in Table 1.

## Data Sources and Limitations

Numerous sources of U.S. data among persons of all ages were analyzed for this article. It is important to recognize that with large, national datasets underreporting and/or misreporting of data can occur. For example, infection-related deaths among individuals with diabetes may not be accurately documented on death certificates when compared to those without diabetes. Similarly, hospital discharge data may not reflect all appropriate diagnoses upon release after inpatient hospitalization. In addition, national data sources often do not reliably differentiate between type 1 and type 2 diabetes, and as a result, all data from persons with diabetes were analyzed as a combined group, which may mask differences in infection risk by diabetes type. Furthermore, in places where the sample size is small, generalizability to all subpopulations may be limited. Despite these limitations, the information available through national datasets using International Classification of Diseases, Ninth or Tenth Revision (ICD-9 or ICD-10) codes (Appendix Table A1) to compute infection rates provides important information to understand the relationship between diabetes and infections.

### Healthcare Cost and Utilization Project 1999–2021

The Healthcare Cost and Utilization Project (HCUP) is the largest collection of longitudinal hospital care data in the United States. HCUP is a family of healthcare databases developed through a federal-state-industry partnership and sponsored by the Agency for Healthcare Research and Quality (AHRQ). HCUP brings together data from state organizations, hospital associations, private data organizations, and the federal government to create all-payer, encounter-level healthcare data that can be used to investigate a broad range of health policy issues. Infections were identified using ICD-9 and ICD-10 diagnosis codes, as microbiologic and antibiotic prescription data were not uniformly available in the national datasets. Although this coding-based approach aligns with prior national studies, it may lead to misclassification or underestimation of mild infections.

### National Ambulatory Medical Care Surveys 1999–2022

The National Ambulatory Medical Care Survey (NAMCS) is a national survey designed to meet the need for objective, reliable information about the provision and use of ambulatory medical care services in the United States. Findings are based on a sample of visits to nonfederal, employed, office-based physicians who are primarily engaged in direct patient care. Infections were identified using ICD-9 and ICD-10 diagnosis codes.

### National Vital Statistics System 1999–2023

The National Vital Statistics System (NVSS) is the oldest and most successful example of intergovernmental data sharing in public health. The National Center for Health Statistics (NCHS) collects and disseminates the official vital statistics of the United States. These data are provided through contracts between NCHS and vital registration systems operated in the various jurisdictions legally responsible for the registration of vital events—births, deaths, marriages, divorces, and fetal deaths.

## Overview of Infections in Individuals With Diabetes

In the NVSS 1999–2023, the age-standardized percentage of deaths attributed to any infection ranged from 2.3% to 16.8% among persons with diabetes and 3.5% to 14.6% among persons without diabetes. Respiratory tract infections accounted for the largest proportion of infection-related deaths in both groups, with a pronounced increase observed in 2020–2022 during the COVID-19 pandemic (Figure 1, Appendix Table A2).

Based on data from the HCUP 1999–2021, the age-standardized percentage of hospital discharges listing any infection ranged from 19.5% to 34.9% in persons with diabetes and 12.1% to 23.4% in persons without diabetes (Figures 2, 3, 4, 5, 6, and 7, Appendix Table A3). Before the COVID-19 pandemic, skin and soft tissue infections (SSTIs) were the most frequently listed infections in hospital discharge records for individuals with diabetes, followed by respiratory tract infections. During and after the pandemic, however, respiratory tract infections became the most commonly listed infections in people with diabetes. In contrast, respiratory tract infections consistently represented the largest proportion of infections documented in hospital discharge records among those without diabetes. The sharp increase in UTIs listed in hospital discharge records for individuals with diabetes beginning in 2016 (from 1.7% to 9.8%) is most likely attributable to the transition from ICD-9 to ICD-10 coding in late 2015, which introduced more detailed categories for UTIs and led to more consistent documentation in discharge data, rather than reflecting a sudden epidemiologic surge.

Based on NAMCS data, physician office visits for infection ranged from 1.0% to 5.1% in persons with diabetes compared with 2.5% to 3.7% in persons without diabetes over the time period 1999–2019 (Figure 8, Appendix Table A4). Data on community health center visits in 1999–2022 among persons with or without diabetes are also provided in Appendix Table A4.

## General Infections in Individuals With Diabetes

### Respiratory Tract Infections

#### Influenza and Pneumonia

Individuals with diabetes (type 1, type 2, or gestational) are at high risk for complications, hospitalization, and death from influenza (12,13,14). The Centers for Disease Control and Prevention (CDC) estimates that 30% of adults hospitalized with influenza in the United States in recent seasons had diabetes (15). Observational studies also indicate an increased incidence of influenza in individuals with diabetes (16,17,18). An analysis of HCUP 1999–2021 data showed a higher percentage of hospital discharges listing influenza as a diagnosis in individuals with diabetes compared to individuals without diabetes in recent years (Figure 9, Appendix Table A3). An analysis using data from the National Health and Nutrition Examination Surveys (NHANES) 1999–2010 showed that individuals with diabetes had a 3.6-fold increased risk of influenza- and pneumonia-specific morbidity after adjusting for comorbidities (19).

The typical incubation period for influenza is one to four days. Common signs and symptoms include an abrupt onset of fever, malaise, myalgia, and a nonproductive cough. Molecular assays, such as nucleic acid amplification tests, are preferred for diagnosis due to their high sensitivity and specificity (20). Multiplex reverse transcriptase polymerase chain reactions (RT-PCR) can detect multiple pathogens simultaneously and should be used when both influenza and the severe acute respiratory syndrome coronavirus 2 (SARS-CoV-2; the virus associated with COVID-19) are circulating or when coinfection is suspected.

Individuals with diabetes face significantly worse outcomes from influenza, including higher rates of hospitalization for influenza or pneumonia, increased intensive care unit (ICU) admission, and elevated risk of myocardial infarction following infection (9,17,21). Bacterial co-infection is also frequent, with Staphylococcus aureus and Streptococcus pneumoniae being the most frequent pathogens reported (22,23). However, studies comparing the microbiological differences in bacterial co-infections between patients with and without diabetes are lacking, and further research is needed to better characterize these differences.

Prophylactic influenza vaccination reduces hospital admissions and mortality related to influenza in individuals with diabetes (13). The Advisory Committee on Immunization Practices (ACIP) recommends annual influenza vaccination for all individuals with diabetes age ≥6 months (Table 1). Although not contraindicated, the ACIP advises caution when administering the live attenuated influenza vaccine (LAIV) to individuals with diabetes (24). This is due to concerns that individuals with chronic medical conditions, including diabetes, may have altered immune responses or increased risk of complications from live vaccines. The inactivated vaccine given by intramuscular injection is used most commonly in adults and is preferred in people with diabetes. Available evidence demonstrates that both the immunogenicity and effectiveness of seasonal influenza vaccines in people with diabetes are comparable to those observed in individuals without diabetes (25).

Antiviral treatment is recommended as soon as possible for any patient diagnosed or suspected of influenza who is at higher risk of complications, including those with diabetes (20). Oral or enteric oseltamivir is the preferred antiviral agent for admitted patients (20).

Other viruses, such as respiratory syncytial virus (RSV) and SARS-CoV-2, can also cause severe disease in people with diabetes (26,27). The ACIP recommends a single RSV vaccine for all adults age ≥75 years and for adults age ≥60 years with risk factors for severe diseases, including individuals with diabetes who have end-organ damage (e.g., diabetic retinopathy, nephropathy, neuropathy, or cardiovascular disease) or requiring treatment with insulin or a sodium-glucose cotransporter-2 (SGLT) inhibitor (Table 2) (28).

While high-quality evidence is limited, existing literature suggests that diabetes is associated with an increased risk of community-acquired pneumonia (CAP). One systematic review and meta-analysis reported a pooled relative risk (RR) of 1.64 (95% confidence interval [CI] 1.55–1.73) of CAP in individuals with diabetes compared to individuals without diabetes; however, all 15 studies included in this analysis had a high risk of bias (29). It remains debatable whether in-hospital mortality in patients admitted with CAP is higher in individuals with diabetes compared to those without diabetes (30).

Individuals with diabetes are at high risk for invasive pneumococcal disease, including pneumococcal bacteremia (with or without pneumonia), meningitis, and other focal invasive infections, such as empyema, septic arthritis, and osteomyelitis. One population-based study found that the incidence of invasive pneumococcal disease in adults age 18–64 years with diabetes was 3.5 times higher (95% CI 3.2–3.9) compared to individuals without diabetes (31). Diabetes is also associated with increased mortality in patients with invasive pneumococcal diseases (hazard ratio [HR] 1.91, 95% CI 1.23–3.03) (32).

Pneumococcal vaccination is recommended for all children, adults age ≥50 years, and adults age ≥19 years with certain immunocompromising conditions, including diabetes (Table 2) (33).

Evidence from randomized trials demonstrates vaccine efficacy in diabetic populations: post-hoc analysis of the CAPiTA trial showed that PCV13 significantly reduced vaccine-type pneumonia hospitalizations in adults with diabetes age ≥65 years (odds ratio [OR] 0.237, 95% CI 0.008–0.704, p=0.002) (34). Observational studies with PPV23 show effectiveness within the first-year post-vaccination (OR 0.63, 95% CI 0.45–0.89 for pneumonia hospitalization), though protection appears to wane thereafter (35).

Important differences in vaccine immune responses exist between diabetic and nondiabetic populations. Studies in type 1 diabetes demonstrate impaired responses to T cell-dependent protein antigens, while responses to pneumococcal polysaccharide antigens (PPV23) remain intact (36,37). For conjugate vaccines, which elicit T cell-dependent responses, antibody levels decline more rapidly in people with type 2 diabetes at 8 months post-vaccination compared to individuals without diabetes (38). In children with type 1 diabetes, protection against pneumococcal colonization from PCV7 vaccination in infancy was not effective after several years, further supporting the need for booster doses to maintain immunity in this population (39). While additional booster immunizations have been shown to overcome impaired vaccine responses to T cell-dependent antigens in type 1 diabetes in controlled studies with other vaccines, clinical data demonstrating that pneumococcal vaccine boosters improve clinical outcomes in populations with diabetes are lacking (36).

#### Sinusitis and Bronchitis

No direct comparative data are available to determine whether individuals with diabetes are more likely to develop bacterial sinusitis and bronchitis than those without diabetes. While sinusitis and bronchitis are predominantly managed in ambulatory care settings, comparative data from outpatient visits is lacking. Analysis of HCUP data from 1999–2021 shows similar rates of hospital discharges for sinusitis and bronchitis in individuals with and without diabetes (Figure 10, Appendix Table A3).

#### COVID-19

Diabetes has been recognized as a risk factor for severe disease since the early days of the COVID-19 pandemic (Figure 11, Appendix Table A3) (40,41). An early study of 450 people admitted with COVID-19 found that diabetes was associated with greater odds of ICU admission (OR 1.59, 95% CI 1.01–2.52), mechanical ventilation (OR 1.97, 95% CI 1.21–3.20), and death (OR 2.02, 95% CI 1.01–4.03) after adjusting for comorbidities (42). However, the accumulation of natural immunity in the population, emergence of less virulent viral variants, expanded therapeutic options, improvements in COVID-19 management, and increased vaccination rates have since led to a reduction in disease severity across all patients, including those with diabetes. Though it remains unclear whether diabetes is associated with a higher risk of acquiring COVID-19, diabetes is associated with worse outcomes for individuals who contract COVID-19 (41).

COVID-19 can precipitate diabetic ketoacidosis (DKA), hyperosmolar hyperglycemic state, and severe insulin resistance (a pathophysiological state in which cells fail to respond normally to insulin, requiring higher insulin levels to achieve glucose uptake and maintain normoglycemia), even in patients without a history of diabetes (43). A systematic review reported that hyperglycemia was more strongly associated with in-hospital mortality (adjusted OR 1.28, 95% CI 1.09–1.50) and ICU admission (crude OR 1.82, 95% CI 1.17–2.84) than diabetes (44). Severe insulin resistance has also been observed in critically ill patients with COVID-19, which may improve with the resolution of infection.

Some studies have suggested an increased incidence of diabetes following COVID-19. A meta-analysis of nine studies with nearly 40 million participants found that the relative risk of diabetes after COVID-19 infection was elevated (RR 1.62, 95% CI 1.45–1.80), with increased risk for individuals with both type 1 diabetes (RR 1.48, 95% CI 1.26–1.75) and type 2 diabetes (RR 1.70, 95% CI 1.32–2.19) (45). Another systematic review and meta-analysis of children and adolescents found an increase in type 1 diabetes incidence in the first year of the pandemic compared with the pre-pandemic period (incidence rate ratio [IRR] 1.14, 95% CI 1.08–1.21), with elevated incidence persisting in the second year (IRR 1.27, 95% CI 1.18–1.37) (46). An analysis of U.S. veterans who survived the first 30 days after a COVID-19 diagnosis showed a significant increase in the incidence of diabetes at 6 months (HR 8.23, 95% CI 6.36–9.95) (47). However, a more recent study of U.S. veterans with incident diabetes found that those with SARS-CoV-2 infection had a 22% higher chance of diabetes remission (RR 1.22, 95% CI 1.14–1.29), with this association attenuated among nonhospitalized participants (RR 1.11, 95% CI 1.04–1.20), suggesting that increased surveillance or transient hyperglycemia rather than permanent metabolic dysfunction may explain some COVID-associated diabetes cases (48).

Post-COVID conditions (PCC), also known as postacute sequelae of SARS-CoV-2 (PASC) or long COVID, are chronic conditions that may develop after SARS-CoV-2 infection and persist for at least 3 months. These conditions can present as continuous, relapsing, remitting, or progressive disease affecting one or more organ systems. Some studies suggest that diabetes is a risk factor for PCC, though definitive evidence is lacking (49,50).

Antiviral treatments are recommended for individuals with diabetes diagnosed with COVID-19, particularly if multiple risk factors for severe disease are present. These therapies are most effective when administered early after symptom onset. Ambulatory treatment options include nirmatrelvir/ritonavir, molnupiravir, and remdesivir (51). Steroids are recommended only for patients hospitalized with severe or critical COVID-19 who require supplemental oxygen or ventilatory support.

The ACIP recommends COVID-19 vaccination for all individuals age ≥6 months after shared clinical decision-making with healthcare providers (52). Discussions should emphasize that the risk-benefit of vaccination is highest for those at an increased risk for severe COVID-19, including individuals with diabetes. In the United States, two mRNA vaccines (Moderna COVID-19 vaccine and Pfizer-BioNTech COVID-19 vaccine) and an adjuvanted recombinant protein vaccine (Novavax COVID-19 vaccine) are available (53). Individuals with diabetes, regardless of type or vaccination status, generally show lower antibody responses and immunogenicity to COVID-19 vaccination (54) compared to those without diabetes, though most still achieve seroconversion after full vaccination. Despite lower immunogenicity, COVID-19 vaccines remain effective in reducing severe disease and death in patients with diabetes, though vaccine effectiveness is modestly lower and breakthrough infection may be more frequent in this group (55).

### Urinary Tract Infections

#### Asymptomatic Bacteriuria

Asymptomatic bacteriuria (ASB) is a significant concern in patients with type 2 diabetes, given their heightened vulnerability to infections, particularly those affecting the urinary tract. The Infectious Diseases Society of America (IDSA) defines ASB as the presence of one or more species of bacteria growing in the urine at specified quantitative counts (≥10^5^ colony-forming units [CFU]/mL or ≥10^8^ CFU/L), irrespective of the presence of pyuria, in the absence of signs or symptoms attributable to UTI (56).

Studies of the global prevalence and management of ASB in type 2 diabetes patients have shown regional variations. For example, the prevalence of ASB in patients with type 2 diabetes in rural southwestern Nigeria is 26.1%, with Escherichia coli being the most commonly isolated pathogen (57). In a prospective case control study in India, the prevalence of ASB was significantly higher in both men and women with diabetes compared with controls (17.5% in patients with type 2 diabetes vs. 10% in controls, p=0.015) (58). A meta-analysis of more than 4,000 patients further highlighted the prevalence and risk factors associated with ASB in type 2 diabetes, showing a worldwide prevalence of 23.7% (59).

A number of clinical factors increase the risk of ASB in patients with type 2 diabetes. A meta-analysis demonstrated that patients with ASB were, on average, 3.18 years older than those without ASB (weighted mean difference [WMD] 3.18 years, 95% CI 1.91–4.45, p<0.001), indicating that advancing age is a significant risk factor, likely related to age-associated immune decline and urinary tract changes (59). Similarly, higher glycated hemoglobin (A1C) levels were observed in the ASB group (WMD 0.63%, 95% CI 0.43%–0.84%, p<0.001), reflecting poorer glycemic control and highlighting the role of chronic hyperglycemia in increasing infection susceptibility (59). Longer duration of diabetes was also associated with greater risk (WMD 2.54 years, 95% CI 1.54–5.43, p<0.001), consistent with the cumulative impact of metabolic and vascular complications over time (59). Female sex was a strong independent predictor (OR 1.07, 95% CI 1.02–1.12, p=0.002), aligning with well-established anatomic and microbiologic risk factors (59). Comorbidities and diabetes complications further amplify this vulnerability. Together, these findings underscore the multifactorial nature of ASB risk in people with type 2 diabetes, with age, glycemic control, disease duration, sex, and metabolic factors all contributing to increased susceptibility.

There is no evidence that ASB treatment can reduce the incidence of UTI. The most recent IDSA guidelines recommend that ASB should be screened for and treated only in pregnant women or in individuals prior to undergoing invasive urologic procedures. Treatment is not recommended for healthy women, older women or men, or persons with diabetes, indwelling catheters, or spinal cord injury (56). This recommendation is based on the understanding that treating ASB in these populations does not significantly reduce the risk of developing symptomatic UTI but increases the risk of adverse effects of therapy, including antibiotic resistance.

Despite IDSA guidelines recommending against routine treatment of ASB in patients with diabetes due to an unfavorable risk-benefit profile, emerging evidence continues to highlight its clinical significance. In a prospective cross-sectional study, 400 patients with type 2 diabetes without symptoms of UTI were compared with 200 healthy controls (58). The prevalence of ASB was significantly higher among individuals with type 2 diabetes compared with controls (17.5% vs. 10%) (58). A subset of 64 type 2 diabetes patients with ASB was followed for 6 months; during this period, 21.8% developed symptomatic UTI (58). Independent predictors of progression to infection included postmenopausal status, poor glycemic control, longer duration of diabetes, diabetic nephropathy, and glycosuria (58). Notably, ASB was associated with worsening glycemic control over time, although renal function remained stable during follow-up (58). This study demonstrates that ASB in type 2 diabetes is common, associated with identifiable risk factors, and confers a measurable risk of subsequent symptomatic infection. These findings reinforce the importance of risk stratification and careful clinical monitoring, particularly in high-risk subgroups, while aligning with current guidelines that discourage routine antimicrobial therapy in the absence of symptoms.

The complex interplay between diabetes management and infection risk, particularly in ASB, highlights the importance of early detection, appropriate antibiotic use, and preventive measures to effectively manage these infections in patients with diabetes.

#### Cystitis and Pyelonephritis

Cystitis and pyelonephritis are common UTIs that present unique challenges for individuals with diabetes due to their increased susceptibility to immune and urinary system changes. Symptoms of cystitis include painful and frequent urination without vaginal discharge or irritation and rarely lead to fever. On the other hand, patients with pyelonephritis typically present with more severe symptoms, such as high fever, chills, and back pain. A urine culture is recommended for diagnosing and managing pyelonephritis and recurrent and complicated UTIs.

A study examining the risk of UTIs in individuals with newly diagnosed type 2 diabetes found that UTI diagnosis was more common in subjects with type 2 diabetes than without type 2 diabetes (9.4% vs. 5.7%, p<0.0001) (60). Recurrence of UTI was also more likely in persons with type 2 diabetes (1.6% vs. 0.6%, p<0.0001). In a logistic regression, individuals with type 2 diabetes had a significantly greater likelihood of developing a UTI during follow-up compared with those without type 2 diabetes (adjusted OR 1.54, 95% CI 1.47–1.60) (60). Insulin use and longer duration of diabetes were also associated with increased risk of UTI (61).

Patients with diabetes, particularly those with type 2 diabetes, are at an increased risk of hospitalization due to pyelonephritis. Studies indicate that women with diabetes are 6–15 times more likely to be hospitalized for acute pyelonephritis (APN) compared to women without diabetes, while men with diabetes have a 3.4–17 times higher hospitalization rate than men without diabetes (62). This elevated risk is due to factors such as impaired immune response and more severe infections in individuals with diabetes. A South Korean study using a Health Insurance Review and Assessment Service claim database found that among patients with APN, 12.4% had diabetes (63). The in-hospital mortality rate was higher in patients with diabetes compared to those without (2.6/1,000 events in the diabetes group vs. 0.3/1,000 in the group without diabetes, p<0.001). After controlling for covariates, diabetes was associated with higher in-hospital mortality in APN patients. The impact of diabetes on in-hospital mortality varied significantly with age, with the effect being most significant for individuals age 15–49 years.

#### SGLT2 Inhibitors and UTI Risk

SGLT2 inhibitors increase urinary glucose excretion, which may theoretically promote bacterial growth in the urinary tract and raise the risk of UTIs; however, evidence for this association has been mixed to date. A meta-analysis of 77 randomized controlled trials involving more than 50,000 participants found no significant increase in UTI incidence compared with placebo or other agents (RR 1.05, 95% CI 0.98–1.12) (64). Similarly, major cardiovascular and renal outcome trials (CANVAS, CREDENCE, DECLARE–TIMI, EMPA-REG) did not show a significant difference in UTI rates (65). Observational data have shown more variability. A real-world cohort study in Thailand found a higher incidence of UTIs among SGLT2 inhibitor users (33.5%) compared with nonusers (11.7%), with a hazard ratio of 3.70 (95% CI 2.60–5.29) (66). Other registry-based studies suggest no increased risk of severe or complicated UTIs in SGLT2 inhibitor users (67,68). Current evidence supports continued use of SGLT2 inhibitors with appropriate patient counseling and monitoring rather than avoidance due to UTI concerns.

#### Emphysematous Pyelonephritis in Patients With Diabetes

EPN is a severe and life-threatening necrotizing infection of the renal parenchyma, occurring in people with poorly controlled type 2 diabetes. It is characterized by gas within the kidney tissues and is linked to a high risk of morbidity and mortality (69). Early studies reported an EPN mortality rate as high as 80%; however, data from 2007 found the overall mortality rate has decreased to 25%, ranging from 11% to 42% (70).

The typical clinical presentation of EPN in patients with diabetes includes fever, costovertebral angle tenderness, severe hyperglycemia, and acute kidney injury (AKI) (71). The most common causative organisms are Escherichia coli and Klebsiella pneumoniae, followed by Proteus (72). Risk factors for EPN include longer duration of diabetes, nephropathy, chronic kidney disease (CKD), hypertension, a history of symptomatic UTI in the prior year, renal calculi, and obstruction (73).

Managing EPN in patients with diabetes is challenging due to a lack of consensus on the optimal approach. Patients with diabetes face high complication risks, especially with renal obstruction, worsening azotemia, and recurrent UTIs. These factors, along with poor glycemic control and renal impairment, predict failure in medical management. EPN complications include DKA, hyperosmolar hyperglycemic state, and multiorgan dysfunction (71,72,73). Early, aggressive treatment is essential, especially if septic shock, altered mental status, or renal deterioration occur. Early imaging and a multidisciplinary approach, including antibiotics and surgery, can improve outcomes in patients not responding to standard pyelonephritis therapy (71,72,73).

#### Renal and Perinephric Abscesses

Renal and perinephric abscesses are localized collections of pus that develop either within the kidney (renal abscess) or in the tissue surrounding the kidney (perinephric abscess). These abscesses typically arise from severe bacterial infections, such as complicated UTIs or as a result of direct extension from infections in adjacent organs. They can also occur due to the spread of bacteria via the bloodstream (hematogenous spread).

Patients with diabetes are at a markedly higher risk of developing renal and perinephric abscesses compared to those without diabetes. Studies of renal and perinephric abscesses reveal that diabetes is associated with a longer hospital stay but does not significantly increase the risk of in-hospital mortality. In a cohort study conducted in Taiwan, patients with diabetes had a longer hospital stay by approximately 3.38 days compared to those without diabetes; however, the mortality rates between the two groups were similar, with 2.3% for patients with diabetes and 3.4% for those without diabetes (74). This finding suggests that while diabetes may not worsen immediate mortality outcomes, it complicates recovery, potentially due to factors like impaired immune function, poorer overall health, and higher rates of complications, such as glycemic instability and infection (62,73). Therefore, managing patients with diabetes and these abscesses requires careful attention to reduce hospital stay through aggressive medical and sometimes surgical interventions.

### Skin and Soft Tissue Infections

SSTIs are common in both outpatient and inpatient settings, with patients with diabetes being at higher risk for complications. An analysis of more than 2 million SSTI cases in U.S. health plans (2005–2010) found that 10% occurred in individuals with diabetes, with abscesses/cellulitis being the most common (75). Patients with diabetes had more than five times the complication rate and four times the hospitalization rate compared to those without diabetes. The most frequent complications in hospitalized patients with diabetes included bacteremia and sepsis (Figure 12, Appendix Table A3). These findings highlight the need for targeted prevention efforts, such as blood sugar control, daily skin hygiene, regular foot care, and immediate treatment of any skin wounds, among individuals with diabetes to reduce morbidity and healthcare costs associated with SSTIs (75).

Analysis of HCUP 1999–2021 data found that the average percentage of hospital discharges listing skin and connective tissue infections among individuals with diabetes decreased slightly from a high of 12.2% in 2015 to 10.7% in 2021 (Figure 6, Appendix Table A3). In individuals without diabetes, the average percentage of hospital discharges listing skin and connective tissue infections was 4.1% in 2021.

Several host-related factors in patients with diabetes predispose them to an increased risk of SSTIs, with hyperglycemia serving as the predominant underlying mechanism. Infection rates and associated complications, including mortality, are notably higher in individuals with type 1 diabetes compared to those with type 2 diabetes, directly correlating with the degree of glycemic control in both diabetes types (7).

#### Fungal Skin and Soft Tissue Infections

Fungal skin infections are notably more prevalent among individuals with diabetes (76). Diabetes is recognized as a significant risk factor for the development of onychomycosis, as well as oral and vulvovaginal candidiasis (Figure 13, Appendix Table A3). These infections are clinically relevant due to their high incidence in patients with poorly controlled diabetes (77,78,79).

##### Candidiasis

Candidiasis frequently manifests in patients with diabetes, particularly when glycemic control is inadequate. Oral candidiasis presents with white patches on the tongue, oral mucosa, and throat, while genital candidiasis manifests as pruritus and a burning sensation in the genital area. Diagnosis is typically achieved through clinical examination, microscopic evaluation, and culture techniques (80). The association between diabetes and fungal infections is well established, particularly in the context of urogenital infections like vulvovaginal candidiasis and balanitis, as well as oral candidiasis caused by Candida species. The use of SGLT2 inhibitors has been linked to an increased risk of urogenital colonization by Candida species, predisposing patients to subsequent infection (81).

##### Urogenital Infections

Vulvovaginal candidiasis is characterized by vulvar soreness and pruritus, often accompanied by a thick, cottage cheese-like vaginal discharge (81). In males with diabetes, Candida spp. can cause balanitis or balanoposthitis, presenting as a pruritic rash with sores, erosions, or papules, often accompanied by subpreputial discharge. The relationship between hyperglycemia and Candida proliferation beneath the prepuce is well documented. Although Candida accounts for less than 20% of all balanoposthitis cases, it remains the most common pathogen in males with diabetes (81). Coinfections with other pathogens, including Streptococcus pyogenes, can complicate the clinical presentation. Treatment of candidal balanitis or balanoposthitis includes topical and oral antifungals, such as clotrimazole or fluconazole. Improving hygiene, keeping the area clean and dry, and avoiding harsh soap or scented products are crucial preventive measures. In severe or recurrent cases, circumcision is recommended to reduce future infection (82).

##### Onychomycosis

Onychomycosis, an infection of the nail plate by dermatophytes, yeasts, and nondermatophytic molds, commonly affects both fingernails and toenails in patients with diabetes. Dermatophytes, particularly Trichophyton rubrum and Epidermophyton floccosum, are the predominant causative agents; other possible causative agents are Trichophyton interdigitale and Trichophyton tonsurans. Microsporum spp. is rarely related to onychomycosis episodes. Onychomycosis is highly prevalent in patients with diabetes, affecting approximately one-third of this population. The infection often begins in interdigital spaces before extending to the nails, contributing to significant morbidity in affected individuals. Oral antifungal therapy (terbinafine, itraconazole, and fluconazole) is the most effective treatment. Liver function tests should be monitored, especially with terbinafine and itraconazole. Topical therapy with antifungal agents (efinaconazole, tavaborole, and ciclopirox) along with debridement can be used in mild or limited infections. Combinations of treatments (topical plus systemic treatment) and nail thinning strategies are required to obtain better results in a short time and avoid relapses (79,83).

#### Bacterial Skin and Soft Tissue Infection

Poor glycemic control has been linked to an increased risk of bacterial skin and soft tissue infections (84). Complicated SSTIs (cSSTIs) are of particular concern because skin breakdown in patients with advanced diabetes and peripheral arterial disease provides a portal of entry for bacteria. Patients with diabetes are more likely to be hospitalized with cSSTIs and to experience related complications than patients without diabetes (85).

Suaya et al. conducted a retrospective cohort study using U.S. healthcare claims data, examining 2,227,401 episodes of SSTIs among individuals age 0–64 years enrolled in U.S. health plans between 2005 and 2010 (75). The study found that 10% of these infections occurred in individuals with diabetes. Abscesses and cellulitis were the most common types of infection in individuals with and without diabetes, accounting for 66% and 59% of cases, respectively (p<0.01). Complication rates for SSTIs, including osteomyelitis, gangrene, sepsis, limb amputation, and necrotizing fasciitis (NF), were more than five times higher in individuals with diabetes compared to those without (4.9% vs. 0.8%, p<0.01) in ambulatory settings, and hospitalization rates were also significantly higher among patients with diabetes (4.9% vs. 1.1%, p<0.01). Additionally, 75.6% of SSTIs among patients with diabetes occurred in the 45–64-years age group compared to 31.1% among individuals without diabetes in the same age group (p<0.01) (75).

Of all skin and connective tissue infections, cellulitis and impetigo were the most frequent hospital discharge diagnoses among individuals with diabetes in the United States in 1999–2021 (Figure 14, Appendix Table A3). In superficial ulcerations and cellulitis, Streptococcus species and Staphylococcus aureus (both methicillin-susceptible and methicillin-resistant) are the most common causative bacteria in patients with diabetes. Corynebacterium species may play an important role in biofilm formation and can cause infection known as erythrasma, presenting as shiny, hyperpigmented patches in areas of increased maceration and friction; erythrasma occurs more frequently in individuals with diabetes and obesity (85). Prompt diagnosis, glycemic management, antibiotic therapy, and in some cases, timely surgical debridement are needed to improve outcomes for superficial SSTIs.

#### Diabetic Foot Ulcers and Osteomyelitis

Diabetic foot ulcers arise from a complex interplay of factors, including peripheral neuropathy, peripheral arterial disease, foot deformities, and infections. Foot infections are common and can result in severe consequences. Infected diabetic foot ulcers can be differentiated from noninfected ones by the presence of purulent discharge along with erythema, warmth, and tenderness around the ulcer. More than half of all foot ulcers become infected, making infection the most frequent precursor to lower extremity amputation. The microbial complications associated with these infections can range from superficial cellulitis to chronic osteomyelitis and gangrene requiring amputation. Previously, coverage for polymicrobial infection was recommended for diabetic foot infections; however, current recommendations are that antibiotic therapy is unnecessary for wounds without confirmed soft tissue or bone infections. Mild infections warrant empiric treatment targeting gram-positive cocci, whereas moderate to severe infections, often due to drug-resistant pathogens, may require cultures or biopsies to establish a diagnosis and necessitate the use of broad-spectrum antimicrobials that are effective against aggressive gram-negative aerobes and obligate anaerobes (86).

Diabetic foot infections represent the most common cause of diabetes-related hospitalizations and lower extremity amputations. In cases of acute diabetic foot infection, there is often a delay in identifying the causative pathogen, necessitating the use of empirical antibiotic therapy. The lifetime risk of developing a foot ulcer in patients with diabetes is estimated at approximately 34%, and more than 50% of these ulcers become infected during their course (86).

Foot infections should be clinically diagnosed based on the presence of inflammation or purulence and then categorized according to severity. This classification aids clinicians in determining the appropriate course of action, such as hospitalization, imaging studies, or surgical intervention. Diabetic foot infections can be caused by a variety of pathogens, either individually or in combination, with gram-positive cocci, particularly staphylococci, being the most prevalent. To improve outcomes and prevent amputations, a systematic approach to the management of diabetic foot infections is essential. Without prompt and appropriate treatment, diabetic foot infections can become refractory to therapy or progress to septic gangrene. Among the various classification systems for diabetic foot ulcers, the IDSA/International Working Group on the Diabetic Foot (IWGDF) system is recommended for categorizing infections (Table 3) (86,87).

Since all skin wounds naturally contain microorganisms, their presence alone—even of virulent species—does not necessarily indicate an infection. Therefore, diagnosing a diabetic foot infection must be based on clinical evaluation, with wound cultures used to identify the causative organisms and assess their antibiotic sensitivities (86). Age-standardized hospital discharge data from the HCUP 1999–2021 demonstrate that approximately 4.4% of patients with diabetes had foot ulcers listed on their discharge summaries compared with 0.7% of patients without diabetes (Figure 15, Appendix Table A3).

Osteomyelitis should be suspected in patients with deep, chronic, nonhealing ulcers or exposed bone. In the evaluation of an infected open wound, a probe-to-bone test is recommended. According to the IWGDF guidelines, the diagnostic approach to diabetic foot osteomyelitis should be guided by the patient’s pretest probability (86). In patients with a low likelihood of osteomyelitis, a negative probe-to-bone test effectively excludes the diagnosis, whereas a positive result in high-risk patients strongly supports it (strong recommendation; high-quality evidence). Markedly elevated inflammatory markers, particularly the erythrocyte sedimentation rate, may further suggest osteomyelitis when clinical suspicion exists (weak recommendation; moderate-quality evidence). A definitive diagnosis generally requires histopathologic confirmation and, ideally, microbiological culture of an aseptically obtained bone specimen. This is indicated when the diagnosis remains uncertain or when antibiotic susceptibility data are essential (strong recommendation; moderate-quality evidence). When bone biopsy is not feasible, a probable diagnosis can be established through a combination of findings from the probe-to-bone test, serum inflammatory markers, plain radiography, magnetic resonance imaging (MRI), or radionuclide imaging (strong recommendation, low-quality evidence). Soft tissue or sinus tract cultures should not be used to guide antibiotic therapy, as they do not reliably reflect bone pathogens (strong recommendation, moderate-quality evidence). Plain radiographs are recommended for all cases of nonsuperficial diabetic foot infection (strong recommendation, low-quality evidence). When advanced imaging is warranted, MRI remains the preferred modality; if unavailable or contraindicated, alternative options include white blood cell-labeled radionuclide scintigraphy, single-photon emission computed tomography/computed tomography (SPECT/CT), or fluorine-1-fluorodeoxyglucose positron emission tomography (FDG-PET) (weak recommendation, moderate-quality evidence (86).

In the HCUP 1999–2021, the percentage of hospital discharges listing osteomyelitis in patients diagnosed with diabetes was 1.0% in 2021, after peaking at 1.7% in 2014 and 2015, compared to 0.1% for patients without diabetes (Figure 16, Appendix Table A3).

An interdisciplinary team, including an infectious disease specialist, a vascular or general surgeon or a podiatrist trained in the management of diabetic foot ulcers, and an endocrinologist, is essential for the optimal management of foot ulcers in individuals with diabetes. Initial empiric antimicrobial therapy, adjusted to pathogen-specific treatment once culture results are available, along with surgical debridement and offloading are appropriate strategies depending on the severity of the condition. In severe cases, such as an unsalvageable foot, untreatable infection, or critically ischemic limb, minor amputation performed in a timely manner may prevent future requirements of major amputations.

#### Deep Subcutaneous Tissue Infections

The incidence of NF in the United States is estimated to range from 500 to 1,500 cases annually; however, this figure may be underestimated due to the challenges in diagnosing NF accurately (88,89). NF and Fournier’s gangrene are notably more common among individuals with diabetes, with up to 75% of NF cases occurring in patients with diabetes (90). Analysis of the National Surgical Quality Improvement Database from 2005 to 2008 revealed that 45% of patients with necrotizing soft tissue infections had diabetes. Despite this association, diabetes was not identified as a risk factor for mortality in the same database during the same period (91).

NF often presents with nonspecific superficial signs, such as erythema and edema, making early diagnosis challenging. It is crucial for clinicians to promptly differentiate between cellulitis, which can be managed with antimicrobial therapy, and NF, which necessitates urgent surgical intervention. Delayed treatment of NF can lead to catastrophic outcomes, including limb amputation, organ failure, and a significantly elevated risk of mortality.

Both NF and cellulitis are marked by skin erythema, edema, and warmth, with fever occasionally present. However, patients with cellulitis typically remain hemodynamically stable, whereas those with NF may exhibit extreme tenderness or pain and can rapidly progress to hemodynamic instability and tissue necrosis. Elevated levels of creatine kinase or aspartate aminotransferase may also indicate a deep tissue infection in NF.

Differentiating between cellulitis and NF is particularly challenging due to the often-vague initial presentation of NF. Diagnostic accuracy may be further compromised by factors such as the use of nonsteroidal anti-inflammatory drugs, which can mask key symptoms, including fever, and the severe, disproportionate pain characteristic of NF. Additionally, patients with diabetic neuropathy may not experience the expected level of pain, complicating the clinical assessment further (92).

NF is classified into two main types: polymicrobial (Type I) and monomicrobial (Type II). Type I, the most common form, involves both aerobic and anaerobic bacteria and is prevalent in older adults with chronic conditions. Type II is typically caused by gram-positive bacteria like group A Streptococcus (GAS) and methicillin-resistant Staphylococcus aureus (MRSA), often leading to severe clinical outcomes, such as toxic shock syndrome. While Type I is associated with chronic disease, Type II can occur in individuals without obvious risk factors. Other less common but more virulent pathogens, including Pseudomonas and Vibrio vulnificus, have led to suggestions of a third classification type, although this is not universally accepted. Additionally, NF can be categorized by infection site, with specific forms like Ludwig angina and Fournier’s gangrene, though these distinctions are more relevant for epidemiological purposes than immediate clinical management (92).

Fournier’s gangrene is a specific type of NF that affects the external genitalia and perianal region. It is characterized by thrombosis of the supplying arteries, resulting in gangrene of the skin and subcutaneous tissue. This condition is often associated with severe systemic toxicity and can lead to multiple organ failure (93). A retrospective study conducted by Taken et al. included 65 patients admitted to the emergency surgical unit with Fournier’s gangrene between January 2006 and August 2014. The study analyzed the anatomical sites of gangrene, predisposing factors, etiological factors, and patient outcomes and found that 29 out of the 65 patients (44.6%) had diabetes (94). Necrotizing infections involving muscles, such as clostridial myonecrosis and non-clostridial myonecrosis, have also been described in individuals with diabetes; however, it is not clear whether these infections occur more frequently in individuals with diabetes compared with the general population.

Analysis of HCUP 1999–2021 data showed that approximately 0.8% of patients with diabetes were discharged with Fournier’s gangrene as a diagnosis (Figure 17, Appendix Table A3). In contrast, only 0.1%–0.2% of those without diabetes had Fournier’s gangrene listed as a diagnosis at hospital discharge. Post-marketing surveillance has raised concerns that SGLT inhibitors may be associated with an increased risk of Fournier’s gangrene. Owing to the rarity of this condition, clinical trial data are insufficient to establish a definitive relationship. Consequently, real-world observational studies are needed to better evaluate the potential association between SGLT2 inhibitor use and Fournier’s gangrene in individuals with type 2 diabetes (95).

### Hospital-Acquired Infections

Hyperglycemia impairs immune function, creating an ideal environment for the growth of bacterial pathogens (96). Among individuals with diabetes, acute illness often exacerbates glycemic control, leading to inpatient hyperglycemia, which is associated with a higher risk of hospital-acquired infections (HAIs), prolonged hospital stays, and increased in-hospital mortality (97,98,99).

An analysis of HCUP 1999–2021 data showed that individuals with diabetes have a higher rate of HAIs (Figure 7, Appendix Table A3), including sepsis and postoperative wound infections. While HAIs increased in both groups, individuals with diabetes consistently had higher infection rates, peaking around 2015 before decreasing slightly and then stabilizing. Conversely, despite higher infection rates, mortality associated with HAIs was consistently lower in individuals with diabetes (Figure 18, Appendix Table A2). The reason for higher mortality in patients without diabetes is unclear.

Diabetes is a well-recognized risk factor for postoperative wound infections (Figure 19, Appendix Table A3). In a systematic review and meta-analysis of 94 studies, diabetes was independently associated with increased surgical site infection risk (OR 1.53, 95% predictive interval 1.11–2.12), with a stronger effect observed in cardiac surgery (OR 2.03) (100). Diabetes also increased the risk of infections following abdominal, podiatric, and head and neck surgeries (101,102,103). However, there is conflicting literature regarding the risk of infection following orthopedic procedures (104,105,106). Optimal perioperative glycemic targets have not been established. A systematic review and meta-analysis found that intensive glycemic control during surgery did not reduce all-cause mortality (RR 1.08, 95% CI 0.88–1.33) or infectious complications (RR 0.75, 95% CI 0.55–1.04) compared to conventional glycemic control; however, intensive glycemic control significantly increased the risk of hypoglycemia (RR 3.36, 95% CI 1.69–6.67) (107).

Diabetes is also a major risk factor for catheter-related bloodstream infections (CRBSI). A meta-analysis revealed that individuals with diabetes admitted to the ICU had three times the odds of developing CRBSI (OR 3.06, 95% CI 2.56–3.66) (108). Similarly, diabetes increases the risk of CRBSI in hemodialysis patients (OR 2.52, 95% CI 1.95–3.25) (109). These findings highlight the need for heightened vigilance and preventive measures for individuals with diabetes who have central venous catheters during hospital admissions.

Diabetes is a recognized risk factor for invasive candidiasis in hospitalized patients. Invasive candidiasis refers to systemic Candida infections that can affect the bloodstream, deep tissues, and organs, representing a severe and potentially life-threatening complication (110). A study of nonneutropenic patients admitted to Internal Medicine wards showed that diabetes increased the risk of invasive candidiasis in hospitalized patients by sevenfold (OR 7.31, 95% CI 3.91–13.61) (111). In critically ill patients, a systematic review and meta-analysis demonstrated that diabetes remained independently associated with invasive candidiasis after adjusting for confounding variables, with a pooled adjusted odds ratio of 3.7 (95% CI 2.24–6.1) (112). Invasive candidiasis is associated with high mortality rates, and early recognition and treatment are essential for improving outcomes (113).

Although it remains unclear whether diabetes is a direct risk factor for Clostridioides difficile colonization, diabetes is associated with an increased risk of fulminant C. difficile infection (CDI) following cardiac surgery (OR 1.74, 95% CI 1.15–2.63) (114). Additionally, a meta-analysis identified diabetes as a risk factor for community-acquired CDI (OR 1.15, 95% CI 1.05–1.27) (115), although diabetes does not appear to be associated with higher mortality in CDI (116,117).

Careful management of inpatient hyperglycemia may help reduce the incidence of HAIs. In a cluster randomized trial, four surgical and four medical wards were randomized to receive either usual care or early intervention for hyperglycemia. In the early-intervention wards, patients with hyperglycemia and diabetes were identified within 24 hours of admission and managed by a specialist team, including a diabetologist, endocrinology fellow, and diabetes nurse. The team provided individualized treatment, prescribing subcutaneous insulin and glucose-lowering medications to achieve safe glycemic control while avoiding hyper- or hypoglycemia. By the end of the trial, HAIs were significantly lower in the intervention group (adjusted OR 0.20, 95% CI 0.07–0.58) (118).

### Periodontal Disease

Managing periodontal complications is crucial for improving overall health outcomes in patients with diabetes. Periodontal disease, or gum disease, refers to infections and inflammation of the structures surrounding the teeth, primarily caused by bacterial plaque buildup. It begins with gingivitis, characterized by inflamed, red, and bleeding gums. If untreated, it can progress to periodontitis, where the infection damages deeper tissues, including the bone, potentially leading to tooth loss. Various risk factors like smoking, genetics, and systemic diseases, such as diabetes, exacerbate the severity of periodontal disease.

The prevalence of periodontal disease is significantly higher in patients with diabetes compared to the general population. Individuals with diabetes are three to four times more likely to develop periodontal disease, with higher risks in smokers and those with uncontrolled diabetes (119). A study in North India found that 95.1% of the 427 participants had some degree of periodontal destruction, with severe periodontitis more common among those with poor oral hygiene and poor glycemic control (120). Various factors affect the prevalence of periodontal disease in patients with diabetes. Annual dental visits, being female, and having a college education are associated with a lower risk, while smoking, older age, non-White race, and lower-income are associated with significantly increased risk (121).

Periodontal disease has been associated with tooth loss and reported as more prevalent among people with diabetes than among those without diabetes. The overall prevalence of tooth removal in a study that included 155,280 people was 38.3%. People with diabetes had a significantly higher prevalence of tooth removal. Respondents with diabetes were 1.46 times as likely (95% CI 1.30–1.64) to have at least one tooth removed compared with respondents without diabetes (122).

## Other Infections Associated With Diabetes

### Necrotizing (Malignant) Otitis Externa

NOE is a potentially life-threatening infection of the temporal bone. It was previously known as “malignant otitis externa,” but this terminology was changed to avoid patient misinterpretation and anxiety. The incidence of NOE appears to be rising, potentially due to increasing antibiotic resistance, a growing population of individuals with diabetes, an aging demographic, and heightened clinical awareness of the condition (123). Pseudomonas aeruginosa is the most common causative agent, followed by others including MRSA, Proteus mirabilis, Klebsiella spp., Aspergillus fumigatus, various other gram-negative bacteria, and fungi. Pseudomonas and MRSA are associated with longer hospitalization and increased complications. NOE primarily affects older adults, individuals with diabetes, and/or immunocompromised patients. Advancing age is associated with increased mortality, while African Americans have been found to have higher rates of comorbidities (123,124,125,126).

NOE presents with symptoms like otalgia, otorrhea, presence of granulation tissue, aural fullness, and hearing loss. Facial nerve palsy is a concerning sign associated with higher mortality. A study analyzing 786 NOE cases found a mean hospital length of stay of 18.6 days, with a 9.3% ICU admission rate (124).

Diagnosis of NOE is based on presence of risk factors for immunosuppression (which increases susceptibility), characteristic clinical signs and symptoms along with their duration, and diagnostic studies, including serum inflammatory markers, microbiology studies and imaging modalities, such as CT, MRI, and PET 2‐deoxy‐2‐[fluorine‐18] fluoro‐D‐glucose with CT (18F‐FDG‐PET/CT). 18F-FDG-PET/CT scans are highly sensitive and specific for detecting, localizing, and confirming resolution of NOE compared to other imaging modalities but are limited by their availability and the need for specialized interpretation. Biopsies are helpful in cases unresponsive to empiric antibiotics (125). Timely and accurate diagnosis, combined with appropriate antibiotic therapy, surgical intervention when indicated, and optimization of glycemic control are considered essential to improving outcomes in NOE, although direct evidence linking glycemic control to reduced mortality remains limited (126).

### Rhinocerebral Mucormycosis

Mucormycosis is a severe invasive fungal infection caused by the fungi mucormycetes (previously known as zygomycetes) belonging to the order Mucorales, with the main genera being Rhizopus, Rhizomucor, Liechtheimia, or Mucor (127). These infections are usually spread through inhalation of spores, absorption of infected meals, or inoculation of injured or damaged tissue (128). The incidence of mucormycosis is rising in several countries due to an increasing at-risk population, improved awareness, and the development of novel diagnostic methods. Two large nationwide prospective surveillance studies conducted in France and Greece identified diabetes as a significant underlying host-related factor for the development of mucormycosis, contributing to 7.5% (41/550 cases) and 15.9% (17/107 cases) of cases, respectively (127,129). The majority of the cases were attributed to hematopoietic malignancies (358/550 cases, 65.1%) followed by trauma (44/550 cases, 8.0%). COVID-19 has emerged as one of the newer and significant risk factors for mucormycosis, along with diabetes (128). Mucormycosis was recently added to the World Health Organization (WHO) fungal priority pathogens list as “high priority” concern (127,129,130).

Mucormycosis is classified by the anatomical region affected, including pulmonary, rhinocerebral, cutaneo-articular, orbital, and disseminated forms. Rhinocerebral mucormycosis is the most common type in patients with diabetes, accounting for 46.4% of cases (19 of 41), particularly in those with DKA (127,128,131). Initially the disease may present with a broad spectrum of manifestations, and hence, one proposed algorithm suggests looking for certain red flag signs in patients with diabetes, including sinus pain, cranial nerve palsy, diplopia, proptosis, periorbital swelling, orbital apex syndrome, or palatine ulcer (132). Black eschar, although pathognomonic, may not be present in all cases.

Given the consistently high mortality rate associated with this infection, maintaining a high level of clinical suspicion is crucial for timely diagnosis and aggressive treatment. To reduce mortality, proactive treatment with antifungal medications like amphotericin B and aggressive surgical debridement with direct tissue sampling are essential (133,134). Additionally, stringent glycemic control and management of DKA are necessary, as both have been shown to significantly impact survival outcomes in patients with rhinocerebral mucormycosis (133,135). The workup requires a multidisciplinary approach, incorporating laboratory markers of inflammation and imaging studies, such as CT, MRI, and FDG-PET, to identify the infected zone and plan surgical boundaries.

### Emphysematous Cholecystitis

Emphysematous cholecystitis (EC) is a rare but life-threatening form of acute cholecystitis, characterized by the presence of gas within the gallbladder wall or lumen. This condition, most commonly caused by gas-forming bacteria such as Clostridium perfringens, Escherichia coli, and Bacteroides fragilis, can progress to gangrenous cholecystitis and peritonitis, carrying high morbidity and mortality rates (136). New analyses of hospital discharge listings from the HCUP 1999–2021 demonstrated similar percentages of EC-related discharges (0.1%–0.2%) for those with and without diabetes; thus, diabetes was present in approximately 50% of EC cases, underscoring its role as a key risk factor (Figure 20, Appendix Table A3). These data support a previous report also showing that 50% of patients diagnosed with EC have diabetes (137). This proportion is attributed to ischemic environments, particularly in individuals with diabetic microangiopathy, which reduce tissue perfusion and impair phagocyte mobility, thereby weakening the immune response and facilitating gas-forming bacterial growth (137).

The initial presenting signs of EC include right upper quadrant pain, fever, jaundice, nausea, and vomiting, making it challenging to distinguish from gallstone-associated cholecystitis and cholangitis based on signs and symptoms alone (138). Crepitus on abdominal palpation is a pathognomonic sign, though rarely present. Diagnosis is based on radiographic findings, with a CT scan (preferred) or X-ray revealing a gaseous halo around the gallbladder and a gas-fluid level within the gallbladder (136,137). Ultrasound is less preferred due to its low sensitivity and high operator dependency. Additionally, laboratory investigations—such as inflammatory markers, liver enzymes, and blood and fluid cultures—are crucial for confirming the diagnosis, identifying specific microbes, and tailoring antibiotic treatments accordingly. Treatment involves conservative measures such as broad-spectrum antibiotics, intravenous fluids, and surgical interventions, such as laparoscopic or open cholecystectomy or percutaneous cholecystostomy, depending on the clinical presentation and patient stability.

### Group B Streptococcus Infections

Group B Streptococcus (GBS), or Streptococcus agalactiae, is a gram-positive coccus characterized by a polysaccharide capsule that contains the cell wall-specific Lancefield Group B antigen (139). GBS is an opportunistic bacterium normally found in healthy adults as part of their genitourinary and gastrointestinal flora. In a large systematic review and meta-analysis, the prevalence of GSB was found to be 25% and 20% for rectal and vaginal swabs, respectively (140). Among U.S. adults, the overall incidence of GBS infection has risen from 1.50 per 100,000 population during 1975–1990 to 2.73 in 1991–2005 and further to 3.79 in 2006–2018 (141). Additionally, the incidence increases with age, reaching 9.13 per 100,000 population in adults age ≥50 years and 19.40 per 100,000 population in those age ≥65 years. Between 2008 and 2016, a significant increase was observed in the percentage of patients with GBS infection who had diabetes, rising from 43.5% to 53.4% (141).

GBS has several serotypes. From 2008 to 2016, the prevalence of serotypes Ib, II, and IV increased, while serotypes Ia, III, and V became less common (141). In North America, serotype V was the most common, accounting for 43.48% of isolates from nonpregnant adults. The frequency of serotype Ib doubled, serotype II increased by more than 70%, and serotype IV quadrupled, contributing significantly to the overall rise in infections. Additionally, serotype III was more prevalent in Europe and Asia, while serotype VI was notably present in Asia but rare elsewhere (139,140,141). These shifts in serotype distribution highlight the evolving landscape of GBS infections, particularly in populations with diabetes, underscoring the need for ongoing surveillance and targeted interventions.

GBS can cause invasive disease in neonates, pregnant women, nonpregnant adults with comorbidities, and older adults. In a systematic review and meta-analysis, diabetes was identified as the primary underlying comorbid condition, present in 15%–64% of invasive GBS (iGBS) cases in nonpregnant adults (139). This was followed by cancer and malignancies, and to a lesser extent, cardiovascular disease, hypertension, cirrhosis, kidney disease, obesity, and chronic obstructive pulmonary disease (COPD) (139). Among U.S. adults in 2008–2016, iGBS most commonly manifested as SSTI (34.0%), bacteremia without a focus (32.3%), osteomyelitis (13.3%), pneumonia (10.2%), and septic arthritis (10.2%) (141). Rarely, iGBS presented as intra-abdominal infection (3.1%), endocarditis (2.1%), meningitis (1.15%), or NF (0.5%) (141). Diabetes was associated with iGBS presenting more frequently as SSTIs (141). Fortunately, the case fatality ratio of iGBS has progressively decreased over time, from 15.12%–15.9% during 1975–1989 to 8.8%–11.83% in 1990–2004, and further down to 7.91%–9.9% in 2005–2021 (139,140,141).

Diagnosis of GBS infections requires high clinical suspicion in combination with diagnostic studies, including laboratory investigations and imaging studies, depending on the signs and symptoms with which the patient is presenting. Blood, fluid, and tissue cultures are helpful in identifying the pathogen and the antimicrobial susceptibility to tailor antibiotics and aid in faster recovery. This is important especially as the antimicrobial resistance among GBS isolates has increased over time, with significant resistance observed to tetracycline (up to 95%), erythromycin (up to 54.8%), and clindamycin (up to 43.2%). While most isolates remained susceptible to penicillin, some resistance was noted in a few studies. Additionally, resistance to levofloxacin, linezolid, and vancomycin was rare but present (139,141), highlighting the need for ongoing surveillance and targeted interventions, especially in populations with diabetes.

## Diabetes and Tuberculosis

The link between diabetes and TB is well established, with TB remaining one of the leading causes of death in low- and middle-income countries (2,142). Despite numerous public health efforts to address diabetes, its prevalence continues to rise at an alarming rate. This increase is occurring more rapidly in low- and middle-income countries—regions already heavily impacted by infectious diseases—compared to high-income countries. As of 2021, more than 10.5% of the global adult population, equivalent to 536.6 million individuals, were living with diabetes. This figure is projected to increase to 12.2%, or 783.2 million adults, by 2045 (143). In 2023, the WHO estimated 10.8 million (95% uncertainty interval [UI] 10.1–11.7 million) people fell ill with TB worldwide, of whom 6 million were men, 3.6 million were women, and 1.25 million were children (144). Of these TB patients, 95% live in developing countries, which are also home to 79% of the global population of adults with diabetes (145,146).

Most evidence regarding diabetes as a risk factor for TB comes from case-control studies conducted worldwide. Al-Rifai et al. conducted a meta-analysis of 44 studies, encompassing a total of 58,468,404 individuals from 16 countries, to evaluate the association between diabetes and the risk of active TB (142). The analysis revealed that individuals with diabetes had a 3.59-fold (95% CI 2.25–5.73), 1.55-fold (95% CI 1.39–1.72), and 2.09-fold (95% CI 1.71–2.55) increased risk of active TB in prospective, retrospective, and case-control studies, respectively. The association was influenced by factors such as country income level (3.16-fold in low/middle-income vs. 1.73-fold in high-income countries), background TB incidence (2.05-fold in countries with >50 vs. 1.89-fold in countries with ≤50 TB cases per 100,000 person-years), and geographical region (2.44-fold in Asia vs. 1.71-fold in Europe and 1.73-fold in the United States/Canada). The strength of the association was greater when TB diagnosis was confirmed microbiologically (3.03-fold) and when diabetes was identified through blood testing (3.10-fold) or in cases of uncontrolled diabetes (3.30-fold). Overall, diabetes was associated with a twofold to fourfold increased risk of active TB, with the association being more pronounced when based on biological testing rather than medical records or self-reports (142). Another systematic review of 30 studies found that the overall relative risk of developing active TB in patients with diabetes ranged from 1.16 to 7.83 compared to those without diabetes (2,146,147). In a systematic review and meta-analysis including more than 17,000 TB cases, diabetes was associated with an approximately threefold increased risk of TB (148). A fourth systematic review, conducted in accordance with the Meta-analysis Of Observational Studies in Epidemiology (MOOSE) guidelines, included a random-effects meta-analysis of 13 cohort studies (149). The pooled analysis demonstrated that diabetes was associated with an increased risk of TB, with a relative risk of 3.11 (95% CI 2.27–4.26). Notably, the relative risk varied by region. It was lower in North America (RR 1.46) compared with Central America (RR 6.00), Europe (RR 4.40), and Asia (RR 3.11). Meta-regression analysis was subsequently performed to assess whether geographic region modified the association between diabetes and TB risk. The reported p-values (p=0.006 for Central America, p=0.004 for Europe, and p=0.03 for Asia) represent the statistical significance of the regional differences—that is, they indicate that region acted as a significant effect modifier of the diabetes-TB association (149).

Clinically, diabetes, particularly when poorly controlled, is linked to a more severe and contagious TB infection compared to the general population. TB in individuals with diabetes (TB-DM) is more frequently associated with pulmonary TB, rather than extrapulmonary forms of the disease, when compared to other conditions that compromise the immune system. Extrapulmonary TB is still more common in TB-DM individuals compared to individuals with TB without diabetes. TB-DM is also characterized by an increased occurrence of lung cavitations, positive sputum smears at diagnosis, fever, cough, hemoptysis, and false-negative tuberculin skin test results compared with individuals with TB without diabetes. Diabetes may prolong the duration of smear and culture positivity at the end of the intensive phase of TB treatment (150).

Patients with diabetes are more likely to present with TB affecting the lower lungs (2) and are also more prone to developing multilobar disease and pleural effusion (4). Additionally, diabetes is associated with a higher risk of treatment complications, relapse, and mortality (151). The treatment for TB can exacerbate certain conditions in individuals with diabetes: hyperglycemia may worsen during acute infection, isoniazid can aggravate peripheral neuropathy, and rifampicin may reduce the effectiveness of sulfonylurea drugs. Mortality is also higher among individuals with both diabetes and TB. For instance, data from Maryland showed that among TB-infected individuals, those with diabetes were 6.5–6.7 times more likely to die compared to those without diabetes (2). A meta-analysis reported that diabetes increases the risk of treatment failure in TB patients (OR 1.65, 95% CI 1.12–2.44); additionally, TB-DM patients have 1.74 times higher odds of mortality compared to those with TB without diabetes (95% CI 1.21–2.51) (151).

The relationship between diabetes and drug-resistant TB, including multidrug-resistant TB (MDR-TB), remains unclear. While some studies suggest that individuals with diabetes respond to TB treatment and are not necessarily more likely to develop multidrug resistance (2,4), the relapse rate in patients with diabetes is four times greater than in those without diabetes (147). Contrarily, a systematic review of 30 studies worldwide found that TB-DM patients were 19% more likely to develop MDR-TB compared to TB patients without diabetes (HR <1, 95% CI 0.60–0.96, p<0.001) (152). Similarly, another analysis of 24 observational studies from 15 different countries revealed a significant positive association between diabetes and MDR-TB (OR 1.97, 95% CI 1.58–2.45, I^2^ 38.2%, p-value for heterogeneity=0.031), irrespective of the country’s income level, the type of diabetes, the method of TB or diabetes diagnosis, or the design of the primary studies (153). Nevertheless, two independent studies by Ragouraman et al. (154) and Gautam et al. (151) in 2021 found no evidence of an increased risk of TB recurrence with drug-resistant strains among people with diabetes. This observation underscores the need for further research into the TB-DM population.

TB management in patients with diabetes presents unique challenges despite use of the same standard first-line regimen (isoniazid, rifampin, pyrazinamide, and ethambutol). Current WHO and American Thoracic Society (ATS)/CDC/IDSA guidelines emphasize close clinical and microbiologic follow-up and integrated management of both conditions to improve treatment success and reduce relapse (155,156).

## Mechanisms by Which Diabetes Increases Susceptibility to Infection

### Emphysematous Pyelonephritis

CKD is associated with impaired renal perfusion, reduced clearance of toxins, and impaired immune responses. These factors create an environment in which infections are more likely to progress rapidly and become severe. Chronic structural changes in the renal parenchyma, such as scarring, reduced vascularity, and tubular dysfunction, can limit local host defenses and reduce the effective delivery of antibiotics to infected tissue. Hypertension contributes by accelerating vascular injury and ischemia in renal tissue; it also compounds diabetes-related microvascular damage and diminishes the kidney’s ability to mount an adequate inflammatory or perfusion response. Together, CKD and hypertension increase susceptibility to infection, impair infection clearance, and are associated with more severe presentations and worse outcomes in EPN.

### Skin and Soft Tissue Infections

Persistent hyperglycemia induces mitochondrial dysfunction and enhances the production of reactive oxygen species, which subsequently leads to oxidative stress. Chronic oxidative stress at the cellular level interferes with insulin signaling pathways and amplifies inflammatory responses. Prolonged exposure to hyperglycemia, coupled with oxidative stress, free radical accumulation, and sustained inflammation, contributes to end-organ damage. Furthermore, compromised skin barrier integrity, suboptimal vascularization, and diabetic neuropathy collectively exacerbate the risk of bacterial invasion in patients with diabetes (157).

### Fungal Skin and Soft Tissue Infections

In patients with poorly controlled diabetes, elevated glucose levels in vaginal secretions provide a nutrient-rich environment conducive to the growth of Candida. Additionally, hyperglycemia disrupts normal vaginal microbiota and alters local pH, further enhancing Candida spp. virulence (158). The initial adhesion of Candida to vaginal epithelial cells is critical for colonization and the establishment of infection (159).

### Necrotizing (Malignant) Otitis Externa

The increased risk of NOE in patients with diabetes is primarily thought to be driven by underlying diabetic macroangiopathy and microangiopathy, which disrupt tissue perfusion and cause immunologic and healing dysfunction by preventing chemotaxis of white blood cells. Additionally, the higher pH of cerumen in patients with diabetes creates a more favorable environment for pathogenic growth (126,160).

### Group B Streptococcus Infections

In patients with diabetes, hyperglycemia causes altered immune function, which affects leukocyte function and increases proinflammatory cytokines. This results in impaired chemotaxis, phagocytosis, opsonization, and pathogen response. Peripheral vascular disease and diabetic neuropathy further exacerbate infection risks and poor outcomes by causing sensory loss and impairing wound healing and immune cell migration (85,161). Consequently, patients with diabetes are at higher risk for GBS and other common and atypical infections.

### Tuberculosis

Numerous studies in both animal models and human subjects have explored the potential biological mechanisms underlying the causal association between diabetes and the increased risk of TB. Current data indicate that individuals with diabetes exhibit a higher bacterial load and reduced T helper 1 cell adaptive immunity, characterized by lower production of interferon-γ, interleukin-12, and nitric oxide (2,149). Additionally, monocytes from individuals with diabetes demonstrate impaired chemotaxis, while alveolar macrophages show decreased hydrogen peroxide production, resulting in reduced oxidative killing potential and diminished phagocytosis (147,153). Furthermore, vitamin D deficiency, which impairs immunity against Mycobacterium tuberculosis in mice (149), is also prevalent in human TB patients (162). These findings suggest a causal relationship between diabetes and TB, with hyperglycemia and its impact on physical barriers and immune function playing a significant role (146).

There is also the question of whether TB can lead to hyperglycemia and diabetes. TB patients have higher rates of impaired glucose tolerance compared to community controls (2). Metabolic decompensation due to infection and infection-induced insulin resistance can result in transient hyperglycemia (146,163). However, it remains unclear whether persistent impaired glucose tolerance and diabetes are directly caused by TB or if these conditions are simply newly diagnosed during TB treatment (2).

## Implementing Evidence-Based Care for Infections Associated With Diabetes

The adoption of evidence-based care for diabetes-related infections relies on well-established implementation strategies. Implementation strategies are approaches that address barriers, improve efficiency, and ensure long-term sustainability of an adopted evidence-based intervention or treatment plan (164). Key strategies include comprehensive infection prevention measures, patient education and empowerment, multidisciplinary collaboration, and promoting continuous quality improvement.

### Comprehensive Infection Prevention Strategies

Preventing diabetes-related infections requires a multifaceted approach incorporating strict infection control measures, antimicrobial stewardship, glycemic control, and early detection of complications. In healthcare settings, rigorous hand hygiene protocols, appropriate use of personal protective equipment, and environmental cleaning are essential for minimizing pathogen transmission. Antibiotic stewardship programs help preserve the effectiveness of existing antibiotics, improve patient outcomes, and reduce the spread of resistant bacteria (165).

Optimizing glycemic control is another important strategy. A study examining infection risk and glycemic control found that fasting plasma glucose levels above 200 mg/dL (>11.1 mmol/L) were associated with increased infection-related morbidity and mortality, particularly in older adults with a higher baseline infection risk (166). A review that assessed the effects of intensive insulin therapy with tight glycemic control versus conventional control on infection risk and neurological outcomes in critically ill neurosurgical and neurological patients showed that maintaining target blood glucose levels reduces infection risk and improves neurological outcome (167).

Additional infection prevention measures should be integrated directly into diabetes care. These include: (a) timely and appropriate antibiotic therapy to ensure effective treatment while minimizing resistance; (b) proactive vaccination against influenza and pneumococcal disease, which should be routinely reviewed and administered within diabetes clinics, rather than deferred solely to primary care, to protect at-risk individuals; and (c) early detection and management of foot ulcers, coupled with proper wound care, to prevent complications and reduce the risk of amputations.

### Patient Education and Empowerment

Educating and empowering individuals with diabetes is important for reducing infection risks and improving health outcomes. Effective strategies include raising awareness about infection susceptibility, educating on prevention techniques including vaccinations against influenza and pneumococcal disease, encouraging medication adherence, and supporting regular self-care behaviors, particularly blood glucose monitoring, eating a healthy diet, engaging in regular physical activity, and monitoring feet for cuts, abrasions, or irritations that could lead to infections. These efforts, aside from improving glycemic control, enhance self-management which can help reduce the frequency of infection episodes, prevent secondary complications and decrease the likelihood of emergency room visits and hospitalizations (168). Existing patient education, including strategies and content for Diabetes Self-Management Education and Support (DSMES), could consider an emphasis on infections and risk for infections to maximize prevention using existing models of education.

### Multidisciplinary Team Collaboration

Implementing evidence-based guidelines helps ensure consistency in infection prevention and management, while ongoing training and education keep healthcare providers informed about the latest research and best practices. This integrated approach strengthens proactive infection management and supports personalized diabetes care. Evidence from a systematic review shows that team-based care reduced major amputations in 94% of studies by consistently addressing glycemic control, local wound management, vascular disease, and infection in a timely and coordinated manner among patients with diabetic foot ulcerations (169). Collaboration among physicians, nurses, pharmacists, dietitians, and podiatrists ensures comprehensive, individualized care supported by effective communication and standardized protocols.

### Continuous Quality Improvement

Ensuring that diabetes-related infection care remains effective requires a commitment to continuous quality improvement. Regularly reviewing and updating care protocols based on emerging research and best practices enhance patient outcomes. Monitoring vaccine protocols, infection rates, and other key indicators helps identify trends and areas needing intervention, while audits and feedback sessions enable healthcare teams to evaluate existing strategies and refine them for better results. Fostering a culture of continuous learning promotes collaboration, innovation, and accountability among providers.

To achieve these improvements, the American Diabetes Association recommends aligning diabetes management approaches with the Chronic Care Model (CCM) (170). A 5-year study evaluating effectiveness of CCM in 53,436 individuals with type 2 diabetes in primary care settings found that its implementation significantly reduced the incidence of diabetes-related complications and all-cause mortality (171). Despite various interventions, fragmented healthcare systems, limited clinical information capabilities, service duplication, and poor care coordination continue to hinder optimal diabetes care. The CCM provides a structured framework for improving the prevention and management of diabetes-related infections through six core elements (164):

• Delivery system design – shifting from reactive to proactive, team-based care for coordinated prevention through routine infection risk screening, vaccination review, and early wound care.

• Self-management support – empowering patients to actively participate in their footcare.

• Decision support – applying evidence-based decision tools at the point of care, such as vaccination protocols and antibiotic stewardship guidelines.

• Clinical information systems – utilizing clinical information systems, such as registries, for tracking vaccination status, antibiotic use, and foot examination completion.

• Community resources and policies – strengthening partnerships with local organizations to improve access to wound care, vaccination, infection screening, and diabetes education programs.

• Health systems – fostering a culture focused on quality improvement, which strengthens early detection and management of diabetes-related infections through routine performance monitoring, evidence-based practices, and feedback that enhance infection prevention and patient outcomes.

## Conclusion

This article presents a broad overview of infections associated with diabetes by examining the prevalence of selected infections in persons with and without diabetes. Evidence shows that several infections and causative organisms are more prevalent in individuals diagnosed with diabetes, though no infection appears to occur exclusively in individuals with diabetes. From 1999 to 2023, individuals with diabetes in the United States experienced a higher burden of infections compared to those without diabetes. The adoption of implementation strategies, including patient education and empowerment, multidisciplinary collaboration, comprehensive infection prevention measures, and promoting continuous quality improvement will address barriers, improve efficiency, and ensure long-term sustainability of evidence-based intervention or treatment plans for infections associated with diabetes.

## List of Abbreviations

ACIP: Advisory Committee on Immunization Practices
APN: acute pyelonephritis
ASB: asymptomatic bacteriuria
CAP: community-acquired pneumonia
CCM: Chronic Care Model
CDC: Centers for Disease Control and Prevention
CDI: Clostridioides difficile infection
CI: confidence interval
CKD: chronic kidney disease
COVID-19: coronavirus disease of 2019
CRBSI: catheter-related bloodstream infection
cSSTI: complicated skin and soft tissue infection
CT: computed tomography
DKA: diabetic ketoacidosis
EC: emphysematous cholecystitis
EPN: emphysematous pyelonephritis
FDG-PET: fluorodeoxyglucose positron emission tomography
GBS: group B Streptococcus
HAI: hospital-acquired infection
HCUP: Healthcare Cost and Utilization Project
HR: hazard ratio
ICD-9/10: International Classification of Diseases, Ninth/Tenth Revision
ICU: intensive care unit
IDSA: Infectious Diseases Society of America
iGBS: invasive group B Streptococcus
IWGDF: International Working Group on the Diabetic Foot
MDR-TB: multidrug-resistant tuberculosis
MRI: magnetic resonance imaging
MRSA: methicillin-resistant Staphylococcus aureus
NAMCS: National Ambulatory Medical Care Survey
NF: necrotizing fasciitis
NOE: necrotizing otitis externa
NVSS: National Vital Statistics System
OR: odds ratio
RR: relative risk
RSV: respiratory syncytial virus
SARS-CoV-2: severe acute respiratory syndrome coronavirus 2
SGLT2: sodium-glucose cotransporter-2
SSTI: skin and soft tissue infection
TB: tuberculosis
TB-DM: tuberculosis in individuals with diabetes mellitus
UTI: urinary tract infection
WHO: World Health Organization
WMD: weighted mean difference

## Conversion

Glucose: mg/dL x 0.0555 = mmol/L

## Acknowledgment

This is an update of: Egede LE, Hull BJ, Williams JS: Infections Associated with Diabetes. Chapter 30 in Diabetes in America, 3rd ed. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 17-1468, 2018, p. 30.1–30.25.

## Article History

Received in final form on December 2, 2025.

## References

1 Lichty JA. The acute infections in diabetes mellitus. Trans Am Climatol Clin Assoc. 1915;31:83-89. https://pmc.ncbi.nlm.nih.gov/articles/PMC2306917/?page=2 21408676
2 Dooley KE, Chaisson RE. Tuberculosis and diabetes mellitus: convergence of two epidemics. Lancet Infect Dis. 2009;9(12):737-746. doi:10.1016/S1473-3099(09)70282-8 19926034
3 Tomic D, Shaw JE, Magliano DJ. The burden and risks of emerging complications of diabetes mellitus. Nat Rev Endocrinol. 2022;18(9):525-539. doi:10.1038/s41574-022-00690-7 35668219
4 Peleg AY, Weerarathna T, McCarthy JS, Davis TM. Common infections in diabetes: pathogenesis, management and relationship to glycaemic control. Diabetes Metab Res Rev. 2007;23(1):3-13. doi:10.1002/dmrr.682 16960917
5 Pearson-Stuttard J, Blundell S, Harris T, Cook DG, Critchley J. Diabetes and infection: assessing the association with glycaemic control in population-based studies. Lancet Diabetes Endocrinol. 2016;4(2):148-158. doi:10.1016/S2213-8587(15)00379-4 26656292
6 Johansson M, Åkesson A, Nilsson PM, Melander O. Longitudinal assessment of the impact of prevalent diabetes on hospital admissions and mortality in the general population: a prospective population-based study with 19 years of follow-up. BMC Public Health. 2024;24(1):2948. doi:10.1186/s12889-024-20435-7 39448967
7 Carey IM, Critchley JA, DeWilde S, Harris T, Hosking FJ, Cook DG. Risk of infection in type 1 and type 2 diabetes compared with the general population: a matched cohort study. Diabetes Care. 2018;41(3):513-521. doi:10.2337/dc17-2131 29330152
8 Magliano DJ, Harding JL, Cohen K, Huxley RR, Davis WA, Shaw JE. Excess risk of dying from infectious causes in those with type 1 and type 2 diabetes. Diabetes Care. 2015;38(7):1274-1280. doi:10.2337/dc14-2820 26070592
9 Jang SA, Min Kim K, Jin Kang H, Heo S-J, Sik Kim C, Won Park S. Higher mortality and longer length of stay in hospitalized patients with newly diagnosed diabetes. Diabetes Res Clin Pract. 2024;210:111601. doi:10.1016/j.diabres.2024.111601 38432469
10 Holt RIG, Cockram CS, Ma RCW, Luk AOY. Diabetes and infection: review of the epidemiology, mechanisms and principles of treatment. Diabetologia. 2024;67(7):1168-1180. doi:10.1007/s00125-024-06102-x 38374451
11 Egede LE, Hull BJ, Williams JS. Infections associated with diabetes. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institutes of Health; 2018; 30.1-30.25:chap 30. https://www.ncbi.nlm.nih.gov/books/NBK567992/
12 Mertz D, Kim TH, Johnstone J, et al. Populations at risk for severe or complicated influenza illness: systematic review and meta-analysis. BMJ. 2013;347:f5061. doi:10.1136/bmj.f5061 23974637
13 Dicembrini I, Silverii GA, Clerico A, et al. Influenza: diabetes as a risk factor for severe related-outcomes and the effectiveness of vaccination in diabetic population. A meta-analysis of observational studies. Nutr Metab Cardiovasc Dis. 2023;33(6):1099-1110. doi:10.1016/j.numecd.2023.03.016 37032254
14 Gill PJ, Ashdown HF, Wang K, et al. Identification of children at risk of influenza-related complications in primary and ambulatory care: a systematic review and meta-analysis. Lancet Respir Med. 2015;3(2):139-149. doi:10.1016/S2213-2600(14)70252-8 25481379
15 Centers for Disease Control and Prevention. Flu and People with Diabetes. 2024. Updated March 20, 2024. https://www.cdc.gov/flu/highrisk/diabetes.html
16 Hine JL, de Lusignan S, Burleigh D, et al. Association between glycaemic control and common infections in people with type 2 diabetes: a cohort study. Diabet Med. 2017;34(4):551-557. doi:10.1111/dme.13205 27548909
17 Horswell R, Chu S, Stone AE, et al. Risk of healthcare visits from influenza in subjects with diabetes and impacts of early vaccination. BMJ Open Diabetes Res Care. 2024;12(4):e003841. doi:10.1136/bmjdrc-2023-003841
18 Amer A, Ayoub A, Brousseau É, Auger N. Risk of severe influenza infection in women with a history of pregnancy complications: a longitudinal cohort study. PLoS One. 2024;19(11):e0313653. doi:10.1371/journal.pone.0313653 39536047
19 Li S, Wang J, Zhang B, Li X, Liu Y. Diabetes mellitus and cause-specific mortality: a population-based study. Diabetes Metab J. 2019;43(3):319-341. doi:10.4093/dmj.2018.0060 31210036
20 Uyeki TM, Bernstein HH, Bradley JS, et al. Clinical Practice Guidelines by the Infectious Diseases Society of America: 2018 Update on Diagnosis, Treatment, Chemoprophylaxis, and Institutional Outbreak Management of Seasonal Influenza. Clin Infect Dis. 2019;68(6):895-902. doi:10.1093/cid/ciy874 30834445
21 Lee W-C, Ho M-C, Leu S-W, et al. The impacts of bacterial co-infections and secondary bacterial infections on patients with severe influenza pneumonitis admitted to the intensive care units. J Crit Care. 2022;72:154164. doi:10.1016/j.jcrc.2022.154164 36209697
22 Bartley PS, Deshpande A, Yu P-C, et al. Bacterial coinfection in influenza pneumonia: rates, pathogens, and outcomes. Infect Control Hosp Epidemiol. 2022;43(2):212-217. doi:10.1017/ice.2021.96 33890558
23 Klein EY, Monteforte B, Gupta A, et al. The frequency of influenza and bacterial coinfection: a systematic review and meta-analysis. Influenza Other Respir Viruses. 2016;10(5):394-403. doi:10.1111/irv.12398 27232677
24 Centers for Disease Control and Prevention. Prevention and Control of Seasonal Influenza with Vaccines: Recommendations of the Advisory Committee on Immunization Practices (ACIP)—United States, 2025–26 Influenza Season. 2024. Updated August 28, 2025. https://www.cdc.gov/mmwr/volumes/74/wr/mm7432a2.htm?s_cid=OS_mm7432a2_w
25 Dos Santos G, Tahrat H, Bekkat-Berkani R. Immunogenicity, safety, and effectiveness of seasonal influenza vaccination in patients with diabetes mellitus: a systematic review. Hum Vaccin Immunother. 2018;14(8):1853-1866. doi:10.1080/21645515.2018.1446719 29517396
26 Havers FP, Whitaker M, Melgar M, et al. Characteristics and outcomes among adults aged ≥60 years hospitalized with laboratory-confirmed respiratory syncytial virus—RSV-NET, 12 States, July 2022–June 2023. MMWR Morb Mortal Wkly Rep. 2023;72(40):1075-1082. doi:10.15585/mmwr.mm7240a1 37796742
27 Falsey AR, Hennessey PA, Formica MA, Cox C, Walsh EE. Respiratory syncytial virus infection in elderly and high-risk adults. N Engl J Med. 2005;352(17):1749-1759. doi:10.1056/NEJMoa043951 15858184
28 Centers for Disease Control and Prevention. RSV Vaccine Guidance for Adults. 2025. Updated July 8, 2025. https://www.cdc.gov/rsv/hcp/vaccine-clinical-guidance/adults.html
29 Brunetti VC, Ayele HT, Yu OHY, Ernst P, Filion KB. Type 2 diabetes mellitus and risk of community-acquired pneumonia: a systematic review and meta-analysis of observational studies. CMAJ Open. 2021;9(1):E62-E70. doi:10.9778/cmajo.20200013
30 Lopez-de-Andres A, Albaladejo-Vicente R, de Miguel-Diez J, et al. Incidence and outcomes of hospitalization for community-acquired, ventilator-associated and non-ventilator hospital-acquired pneumonias in patients with type 2 diabetes mellitus in Spain. BMJ Open Diabetes Res Care. 2020;8(1):e001447. doi:10.1136/bmjdrc-2020-001447
31 Weycker D, Farkouh RA, Strutton DR, Edelsberg J, Shea KM, Pelton SI. Rates and costs of invasive pneumococcal disease and pneumonia in persons with underlying medical conditions. BMC Health Serv Res. 2016;16:182. doi:10.1186/s12913-016-1432-4 27177430
32 Garrouste-Orgeas M, Azoulay E, Ruckly S, et al. Diabetes was the only comorbid condition associated with mortality of invasive pneumococcal infection in ICU patients: a multicenter observational study from the Outcomerea research group. Infection. 2018;46(5):669-677. doi:10.1007/s15010-018-1169-6 29974388
33 Kobayashi M, Leidner AJ, Gierke R, et al. Expanded recommendations for use of pneumococcal conjugate vaccines among adults aged >/=50 years: recommendations of the Advisory Committee on Immunization Practices - United States, 2024. MMWR Morb Mortal Wkly Rep. 2025;74(1):1-8. doi:10.15585/mmwr.mm7401a1 39773952
34 Huijts SM, van Werkhoven CH, Bolkenbaas M, Grobbee DE, Bonten MJM. Post-hoc analysis of a randomized controlled trial: diabetes mellitus modifies the efficacy of the 13-valent pneumococcal conjugate vaccine in elderly. Vaccine. 2017;35(34):4444-4449. doi:10.1016/j.vaccine.2017.01.071 28410813
35 Del Riccio M, Boccalini S, Cosma C, et al. Effectiveness of pneumococcal vaccination on hospitalization and death in the adult and older adult diabetic population: a systematic review. Expert Rev Vaccines. 2023;22(1):1179-1184. doi:10.1080/14760584.2023.2286374 37990793
36 Eibl N, Spatz M, Fischer GF, et al. Impaired primary immune response in type-1 diabetes: results from a controlled vaccination study. Clin Immunol. 2002;103(3 Pt 1):249-259. doi:10.1006/clim.2002.5220 12173299
37 Ruben FL, Nagel J, Fireman P. Antitoxin responses in the elderly to tetanus-diphtheria (TD) immunization. Am J Epidemiol. 1978;108(2):145-149. doi:10.1093/oxfordjournals.aje.a112598 707475
38 Ahmad I, Burton R, Arshad R, Younis BB, Mirza S. Humoral immune response to 10-valent pneumococcal conjugate vaccine (PCV10) in individuals with type 2 diabetes mellitus. Vaccine. 2025;55:127029. doi:10.1016/j.vaccine.2025.127029 40127571
39 Principi N, Iughetti L, Cappa M, et al. Streptococcus pneumoniae oropharyngeal colonization in school-age children and adolescents with type 1 diabetes mellitus: impact of the heptavalent pneumococcal conjugate vaccine. Hum Vaccin Immunother. 2016;12(2):293-300. doi:10.1080/21645515.2015.1072666 26575615
40 CDC COVID-19 Response Team. Preliminary estimates of the prevalence of selected underlying health conditions among patients with coronavirus disease 2019—United States, February 12–March 28, 2020. MMWR Morb Mortal Wkly Rep. 2020;69(13):382-386. doi:10.15585/mmwr.mm6913e2 32240123
41 Hartmann-Boyce J, Rees K, Perring JC, et al. Risks of and from SARS-CoV-2 infection and COVID-19 in people with diabetes: a systematic review of reviews. Diabetes Care. 2021;44(12):2790-2811. doi:10.2337/dc21-0930 34711637
42 Seiglie J, Platt J, Cromer SJ, et al. Diabetes as a risk factor for poor early outcomes in patients hospitalized with COVID-19. Diabetes Care. 2020;43(12):2938-2944. doi:10.2337/dc20-1506 32847827
43 Khunti K, Del Prato S, Mathieu C, Kahn SE, Gabbay RA, Buse JB. COVID-19, hyperglycemia, and new-onset diabetes. Diabetes Care. 2021;44(12):2645-2655. doi:10.2337/dc21-1318 34625431
44 Barmanray RD, Cheuk N, Fourlanos S, Greenberg PB, Colman PG, Worth LJ. In-hospital hyperglycemia but not diabetes mellitus alone is associated with increased in-hospital mortality in community-acquired pneumonia (CAP): a systematic review and meta-analysis of observational studies prior to COVID-19. BMJ Open Diabetes Res Care. 2022;10(4):e002880. doi:10.1136/bmjdrc-2022-002880
45 Zhang T, Mei Q, Zhang Z, et al. Risk for newly diagnosed diabetes after COVID-19: a systematic review and meta-analysis. BMC Med. 2022;20(1):444. doi:10.1186/s12916-022-02656-y 36380329
46 D’Souza D, Empringham J, Pechlivanoglou P, Uleryk EM, Cohen E, Shulman R. Incidence of diabetes in children and adolescents during the COVID-19 pandemic: a systematic review and meta-analysis. JAMA Netw Open. 2023;6(6):e2321281. doi:10.1001/jamanetworkopen.2023.21281 37389869
47 Al-Aly Z, Xie Y, Bowe B. High-dimensional characterization of post-acute sequelae of COVID-19. Nature. 2021;594(7862):259-264. doi:10.1038/s41586-021-03553-9 33887749
48 Wander PL, Lowy E, Korpak A, Beste LA, Kahn SE, Boyko EJ. SARS-CoV-2 infection is associated with higher chance of diabetes remission among veterans with incident diabetes. PLoS One. 2025;20(2):e0317348. doi:10.1371/journal.pone.0317348 39970150
49 Su Y, Yuan D, Chen DG, et al. Multiple early factors anticipate post-acute COVID-19 sequelae. Cell. 2022;185(5):881-895.e20. doi:10.1016/j.cell.2022.01.014 35216672
50 Fernández-de-Las-Peñas C, Guijarro C, Torres-Macho J, et al. Diabetes and the risk of long-term post-COVID symptoms. Diabetes. 2021;70(12):2917-2921. doi:10.2337/db21-0329 34580087
51 Bhimraj A, Morgan RL, Shumaker AH, et al. Infectious Diseases Society of America Guidelines on the Treatment and Management of Patients With COVID-19 (September 2022). Clin Infect Dis. 2024;78(7):e250-e349. doi:10.1093/cid/ciac724 36063397
52 Roper LE, Godfrey M, Link-Gelles R, et al. Use of additional doses of 2024–2025 COVID-19 vaccine for adults aged ≥65 years and persons aged ≥6 months with moderate or severe immunocompromise: recommendations of the Advisory Committee on Immunization Practices — United States, 2024. MMWR Morb Mortal Wkly Rep. 2024;73(49):1118-1123. doi:10.15585/mmwr.mm7349a2
53 Panagiotakopoulos L, Godfrey M, Moulia DL, et al. Use of an additional updated 2023–2024 COVID-19 vaccine dose for adults aged ≥65 years: recommendations of the Advisory Committee on Immunization Practices—United States, 2024. MMWR Morb Mortal Wkly Rep. 2024;73(16):377-381. doi:10.15585/mmwr.mm7316a4 38662708
54 Boroumand AB, Forouhi M, Karimi F, et al. Immunogenicity of COVID-19 vaccines in patients with diabetes mellitus: a systematic review. Front Immunol. 2022;13:940357. doi:10.3389/fimmu.2022.940357 36105809
55 van den Berg JM, Remmelzwaal S, Blom MT, et al. Effectiveness of COVID-19 vaccines in adults with diabetes mellitus: a systematic review. Vaccines (Basel). 2022;11(1):24. doi:10.3390/vaccines11010024 36679869
56 Nicolle LE, Gupta K, Bradley SF, et al. Clinical Practice Guideline for the Management of Asymptomatic Bacteriuria: 2019 Update by the Infectious Diseases Society of America. Clin Infect Dis. 2019;68(10):e83-e110. doi:10.1093/cid/ciy1121 30895288
57 Ibrahim AO, Bello IS, Ajetunmobi OA, et al. Asymptomatic bacteriuria in patients with type 2 diabetes mellitus in rural southwestern Nigeria: a cross-sectional study. J Int Med Res. 2024;52(3). doi:10.1177/03000605241233515
58 Laway BA, Nabi T, Bhat MH, Fomda BA. Prevalence, clinical profile and follow up of asymptomatic bacteriuria in patients with type 2 diabetes—prospective case control study in Srinagar, India. Diabetes Metab Syndr. 2021;15(1):455-459. doi:10.1016/j.dsx.2020.12.043 33601179
59 Dai M, Hua S, Yang J, et al. Incidence and risk factors of asymptomatic bacteriuria in patients with type 2 diabetes mellitus: a meta-analysis. Endocrine. 2023;82(2):263-281. doi:10.1007/s12020-023-03469-6 37599328
60 Fu AZ, Iglay K, Qiu Y, Engel S, Shankar R, Brodovicz K. Risk characterization for urinary tract infections in subjects with newly diagnosed type 2 diabetes. J Diabetes Complications. 2014;28(6):805-810. doi:10.1016/j.jdiacomp.2014.06.009 25161100
61 Boyko EJ, Fihn SD, Scholes D, Abraham L, Monsey B. Risk of urinary tract infection and asymptomatic bacteriuria among diabetic and nondiabetic postmenopausal women. Am J Epidemiol. 2005;161(6):557-564. doi:10.1093/aje/kwi078 15746472
62 Nitzan O, Elias M, Chazan B, Saliba W. Urinary tract infections in patients with type 2 diabetes mellitus: review of prevalence, diagnosis, and management. Diabetes Metab Syndr Obes. 2015;8:129-136. doi:10.2147/DMSO.S51792 25759592
63 Kim B, Myung R, Kim G-H, Lee M-J, Kim J, Pai H. Diabetes mellitus increases mortality in acute pyelonephritis patients: a population study based on the National Health Insurance Claim Data of South Korea for 2010–2014. Infection. 2020;48(3):435-443. doi:10.1007/s15010-020-01419-2 32301098
64 Li D, Wang T, Shen S, Fang Z, Dong Y, Tang H. Urinary tract and genital infections in patients with type 2 diabetes treated with sodium-glucose co-transporter 2 inhibitors: a meta-analysis of randomized controlled trials. Diabetes Obes Metab. 2017;19(3):348-355. doi:10.1111/dom.12825 27862830
65 Pishdad R, Auwaerter PG, Kalyani RR. Diabetes, SGLT-2 inhibitors, and urinary tract infection: a review. Curr Diab Rep. 2024;24(5):108-117. doi:10.1007/s11892-024-01537-3 38427314
66 Uitrakul S, Aksonnam K, Srivichai P, Wicheannarat S, Incomenoy S. The incidence and risk factors of urinary tract infection in patients with type 2 diabetes mellitus using SGLT2 inhibitors: a real-world observational study. Medicines (Basel). 2022;9(12):59. doi:10.3390/medicines9120059 36547992
67 Wiegley N, So PN. Sodium-glucose cotransporter 2 inhibitors and urinary tract infection: is there room for real concern? Kidney360. 2022;3(11):1991-1993. doi:10.34067/KID.0005722022 36514393
68 Ljungberg C, Kristensen FPB, Dalager-Pedersen M, et al. Risk of urogenital infections in people with type 2 diabetes initiating SGLT2is versus GLP-1RAs in routine clinical care: a Danish cohort study. Diabetes Care. 2025;48(6):945-954. doi:10.2337/dc24-2169 40173095
69 Nishikawara M, Harada M, Yamazaki D, Kakegawa T, Hashimoto K, Kamijo Y. A case of emphysematous pyelonephritis in an older man with poorly controlled type 2 diabetes mellitus. CEN Case Rep. 2024;13(3):161-167. doi:10.1007/s13730-023-00821-7 37737333
70 Falagas ME, Alexiou VG, Giannopoulou KP, Siempos II. Risk factors for mortality in patients with emphysematous pyelonephritis: a meta-analysis. J Urol. 2007;178(3 Pt 1):880-885. doi:10.1016/j.juro.2007.05.017 17631348
71 Rafiq N, Nabi T, Rasool S, Sheikh RY. A prospective study of emphysematous pyelonephritis in patients with type 2 diabetes. Indian J Nephrol. 2021;31(6):536-543. doi:10.4103/ijn.IJN_411_19 35068760
72 Bhat SK, Srivastava A, Ansari NA, et al. Emphysematous pyelonephritis in type 2 diabetes—clinical profile and management. Saudi J Kidney Dis Transpl. 2021;32(6):1646-1654. doi:10.4103/1319-2442.352425 35946277
73 Nabi T, Rafiq N, Rahman MHU, Rasool S, Wani NUD. Comparative study of emphysematous pyelonephritis and pyelonephritis in type 2 diabetes: a single-centre experience. J Diabetes Metab Disord. 2020;19(2):1273-1282. doi:10.1007/s40200-020-00640-y 33553028
74 Ko MC, Chiu AW-H, Liu C-C, et al. Effect of diabetes on mortality and length of hospital stay in patients with renal or perinephric abscess. Clinics (Sao Paulo). 2013;68(8):1109-1114. doi:10.6061/clinics/2013(08)08 24037006
75 Suaya JA, Eisenberg DF, Fang C, Miller LG. Skin and soft tissue infections and associated complications among commercially insured patients aged 0–64 years with and without diabetes in the U.S. PLoS One. 2013;8(4):e60057. doi:10.1371/journal.pone.0060057 23593162
76 Lima AL, Illing T, Schliemann S, Elsner P. Cutaneous manifestations of diabetes mellitus: a review. Am J Clin Dermatol. 2017;18(4):541-553. doi:10.1007/s40257-017-0275-z 28374407
77 Halimi A, Mortazavi N, Memarian A, et al. The relation between serum levels of interleukin 10 and interferon-gamma with oral candidiasis in type 2 diabetes mellitus patients. BMC Endocr Disord. 2022;22(1):296. doi:10.1186/s12902-022-01217-x 36443718
78 Talapko J, Meštrović T, Škrlec I. Growing importance of urogenital candidiasis in individuals with diabetes: a narrative review. World J Diabetes. 2022;13(10):809-821. doi:10.4239/wjd.v13.i10.809 36311997
79 Leung AKC, Lam JM, Leong KF, et al. Onychomycosis: an updated review. Recent Pat Inflamm Allergy Drug Discov. 2020;14(1):32-45. doi:10.2174/1872213X13666191026090713 31738146
80 Bhattacharya S, Sae-Tia S, Fries BC. Candidiasis and mechanisms of antifungal resistance. Antibiotics (Basel). 2020;9(6):312. doi:10.3390/antibiotics9060312 32526921
81 Kalra S, Chawla A. Diabetes and balanoposthitis. J Pak Med Assoc. 2016;66(8):1039-1041.27524547
82 Maatouk I, Hajjar MA, Moutran R. Candida albicans and Streptococcus pyogenes balanitis: diabetes or STI? Int J STD AIDS. 2015;26(10):755-756. doi:10.1177/0956462414555933 26232734
83 Trovato L, Calvo M, De Pasquale R, Scalia G, Oliveri S. Prevalence of onychomycosis in diabetic patients: a case-control study performed at University Hospital Policlinico in Catania. J Fungi (Basel). 2022;8(9):922. doi:10.3390/jof8090922 36135647
84 Polk C, Sampson MM, Roshdy D, Davidson LE. Skin and soft tissue infections in patients with diabetes mellitus. Infect Dis Clin North Am. 2021;35(1):183-197. doi:10.1016/j.idc.2020.10.007 33303332
85 Dryden M, Baguneid M, Eckmann C, et al. Pathophysiology and burden of infection in patients with diabetes mellitus and peripheral vascular disease: focus on skin and soft-tissue infections. Clin Microbiol Infect. 2015;21 Suppl 2:S27-S32. doi:10.1016/j.cmi.2015.03.024 26198368
86 Senneville É, Albalawi Z, van Asten SA, et al. IWGDF/IDSA Guidelines on the Diagnosis and Treatment of Diabetes-Related Foot Infections (IWGDF/IDSA 2023). Clin Infect Dis. 2023:ciad527. doi:10.1093/cid/ciad527 37779457
87 Peters EJ. Pitfalls in diagnosing diabetic foot infections. Diabetes Metab Res Rev. 2016;32 Suppl 1:254-260. doi:10.1002/dmrr.2736 26813617
88 Anaya DA, Dellinger EP. Necrotizing soft-tissue infection: diagnosis and management. Clin Infect Dis. 2007;44(5):705-710. doi:10.1086/511638 17278065
89 Arif N, Yousfi S, Vinnard C. Deaths from necrotizing fasciitis in the United States, 2003–2013. Epidemiol Infect. 2016;144(6):1338-1344. doi:10.1017/S0950268815002745 26548496
90 Rajagopalan S. Serious infections in elderly patients with diabetes mellitus. Clin Infect Dis. 2005;40(7):990-996. doi:10.1086/427690 15824991
91 Mills MK, Faraklas I, Davis C, Stoddard GJ, Saffle J. Outcomes from treatment of necrotizing soft-tissue infections: results from the National Surgical Quality Improvement Program database. Am J Surg. 2010;200(6):790-796. doi:10.1016/j.amjsurg.2010.06.008 21146022
92 Chen LL, Fasolka B, Treacy C. Necrotizing fasciitis: a comprehensive review. Nursing. 2020;50(9):34-40. doi:10.1097/01.NURSE.0000694752.85118.62
93 Aliev SA, Rafiev SF, Rafiev FS, Aliev ES. [Fournier disease in surgeon’s practice] [Article in Russian]. Khirurgiia (Mosk). 2008;(11):58-63. https://pubmed.ncbi.nlm.nih.gov/19301497/
94 Taken K, Oncu MR, Ergun M, et al. Fournier’s gangrene: causes, presentation and survival of sixty-five patients. Pak J Med Sci. 2016;32(3):746-750. doi:10.12669/pjms.323.9798 27375726
95 Wang T, Patel SM, Hickman A, et al. SGLT2 inhibitors and the risk of hospitalization for Fournier’s gangrene: a nested case-control study. Diabetes Ther. 2020;11(3):711-723. doi:10.1007/s13300-020-00771-8 32052281
96 Darwitz BP, Genito CJ, Thurlow LR. Triple threat: how diabetes results in worsened bacterial infections. Infect Immun. 2024;92(9):e0050923. doi:10.1128/iai.00509-23 38526063
97 King JT, Jr., Goulet JL, Perkal MF, Rosenthal RA. Glycemic control and infections in patients with diabetes undergoing noncardiac surgery. Ann Surg. 2011;253(1):158-165. doi:10.1097/SLA.0b013e3181f9bb3a 21135698
98 Umpierrez GE, Isaacs SD, Bazargan N, You X, Thaler LM, Kitabchi AE. Hyperglycemia: an independent marker of in-hospital mortality in patients with undiagnosed diabetes. J Clin Endocrinol Metab. 2002;87(3):978-982. doi:10.1210/jcem.87.3.8341 11889147
99 Björk M, Melin EO, Frisk T, Thunander M. Admission glucose level was associated with increased short-term mortality and length-of-stay irrespective of diagnosis, treating medical specialty or concomitant laboratory values. Eur J Intern Med. 2020;75:71-78. doi:10.1016/j.ejim.2020.01.010 31982283
100 Martin ET, Kaye KS, Knott C, et al. Diabetes and risk of surgical site infection: a systematic review and meta-analysis. Infect Control Hosp Epidemiol. 2016;37(1):88-99. doi:10.1017/ice.2015.249 26503187
101 Wijma AG, Driessens H, Nijkamp MW, Hoogwater FJH, van Dijk PR, Klaase JM. Impact of preoperative diabetes mellitus on postoperative outcomes in elective pancreatic surgery and its implications for prehabilitation practice. Pancreas. 2024;53(3):e274-e279. doi:10.1097/MPA.0000000000002300 38277400
102 Soldevila-Boixader L, Viehöfer A, Wirth S, et al. Risk factors for surgical site infections in elective orthopedic foot and ankle surgery: the role of diabetes mellitus. J Clin Med. 2023;12(4):1608. doi:10.3390/jcm12041608 36836144
103 Patel RV, Randhawa A, Randhawa KS, et al. The impact of diabetes on morbidity and mortality following thyroidectomy. Laryngoscope. 2023;133(12):3628-3632. doi:10.1002/lary.30902 37470297
104 Rich MD, Solaiman RH, Lamba A, Schubert W, Hillard C, Mahajan A. Comorbidities associated with increased likelihood of postoperative surgical site infection in patients treated for hand or finger fracture and/or dislocations. Hand (N Y). 2024;19(2):263-268. doi:10.1177/15589447221120847 36113058
105 Greene ST, McGee TL, Kot TC, Nehete PV, Bhanat EL, Bergin PF. Hemoglobin A1c as a predictor of surgical site infection in patients with orthopaedic trauma. J Am Acad Orthop Surg Glob Res Rev. 2023;7(11):e23.00204. doi:10.5435/JAAOSGlobal-D-23-00204
106 Hoffa MT, Furdock RJ, Moon TJ, Bacharach A, Heimke IM, Vallier HA. Fractures in patients with diabetes mellitus: findings from a 20-year registry at a single level 1 trauma center. J Am Acad Orthop Surg Glob Res Rev. 2024;8(5):e23.00166. doi:10.5435/JAAOSGlobal-D-23-00166
107 Bellon F, Solà I, Gimenez-Perez G, et al. Perioperative glycaemic control for people with diabetes undergoing surgery. Cochrane Database Syst Rev. 2023;8(8):CD007315. doi:10.1002/14651858.CD007315.pub3 37526194
108 Huang H, Chang Q, Zhou Y, Liao L. Risk factors of central catheter bloodstream infections in intensive care units: a systematic review and meta-analysis. PLoS One. 2024;19(4):e0296723. doi:10.1371/journal.pone.0296723 38652718
109 Guo H, Zhang L, He H, Wang L. Risk factors for catheter-associated bloodstream infection in hemodialysis patients: a meta-analysis. PLoS One. 2024;19(3):e0299715. doi:10.1371/journal.pone.0299715 38536779
110 Rodrigues CF, Rodrigues ME, Henriques M. Candida sp. infections in patients with diabetes mellitus. J Clin Med. 2019;8(1):76. doi:10.3390/jcm8010076 30634716
111 Falcone M, Tiseo G, Tascini C, et al. Assessment of risk factors for candidemia in non-neutropenic patients hospitalized in Internal Medicine wards: a multicenter study. Eur J Intern Med. 2017;41:33-38. doi:10.1016/j.ejim.2017.03.005 28314653
112 Thomas-Rüddel DO, Schlattmann P, Pletz M, Kurzai O, Bloos F. Risk factors for invasive Candida infection in critically ill patients: a systematic review and meta-analysis. Chest. 2022;161(2):345-355. doi:10.1016/j.chest.2021.08.081 34673022
113 Kollef M, Micek S, Hampton N, Doherty JA, Kumar A. Septic shock attributed to Candida infection: importance of empiric therapy and source control. Clin Infect Dis. 2012;54(12):1739-1746. doi:10.1093/cid/cis305 22423135
114 Vondran M, Schack S, Garbade J, et al. Evaluation of risk factors for a fulminant Clostridium difficile infection after cardiac surgery: a single-center, retrospective cohort study. BMC Anesthesiol. 2018;18(1):133. doi:10.1186/s12871-018-0597-2 30257648
115 Furuya-Kanamori L, Stone JC, Clark J, et al. Comorbidities, exposure to medications, and the risk of community-acquired Clostridium difficile infection: a systematic review and meta-analysis. Infect Control Hosp Epidemiol. 2015;36(2):132-141. doi:10.1017/ice.2014.39 25632995
116 López-de-Andrés A, Esteban-Vasallo MD, de Miguel-Díez J, et al. Incidence and in-hospital outcomes of Clostridium difficile infection among type 2 diabetes patients in Spain. Int J Clin Pract. 2018;72(10):e13251. doi:10.1111/ijcp.13251 30216649
117 Stewart DB, Hollenbeak CS. Clostridium difficile colitis: factors associated with outcome and assessment of mortality at a national level. J Gastrointest Surg. 2011;15(9):1548-1555. doi:10.1007/s11605-011-1615-6 21720924
118 Kyi M, Colman PG, Wraight PR, et al. Early intervention for diabetes in medical and surgical inpatients decreases hyperglycemia and hospital-acquired infections: a cluster randomized trial. Diabetes Care. 2019;42(5):832-840. doi:10.2337/dc18-2342 30923164
119 Turner C. Diabetes mellitus and periodontal disease: a new perspective. Prim Dent J. 2024;13(2):73-78. doi:10.1177/20501684241254654
120 Singh M, Bains VK, Jhingran R, et al. Prevalence of periodontal disease in type 2 diabetes mellitus patients: a cross-sectional study. Contemp Clin Dent. 2019;10(2):349-357. doi:10.4103/ccd.ccd_652_18 32308302
121 Vu GT, Shakib S, King C, Gurupur V, Little BB. Association between uncontrolled diabetes and periodontal disease in US adults: NHANES 2009–2014. Sci Rep. 2023;13(1):16694. doi:10.1038/s41598-023-43827-y 37794165
122 Kapp JM, Boren SA, Yun S, LeMaster J. Diabetes and tooth loss in a national sample of dentate adults reporting annual dental visits. Prev Chronic Dis. 2007;4(3):A59. https://www.cdc.gov/pcd/issues/2007/jul/06_0134.htm 17572963
123 Lodhi S, Dodgson K, Dykes M, et al. Diagnostic criteria and core outcome set development for necrotising otitis externa: the COSNOE Delphi consensus study. J Laryngol Otol. 2024;138(9):913-920. doi:10.1017/S0022215124000513 38644734
124 Hatch JL, Bauschard MJ, Nguyen SA, Lambert PR, Meyer TA, McRackan TR. Malignant otitis externa outcomes: a study of the University HealthSystem Consortium database. Ann Otol Rhinol Laryngol. 2018;127(8):514-520. doi:10.1177/0003489418778056 29962250
125 Ahmed AA, Rashid S, Gupta VK, Molony NC, Gupta KK. The diagnostic conundrum in necrotizing otitis externa. World J Otorhinolaryngol Head Neck Surg. 2024;10(1):59-65. doi:10.1002/wjo2.100 38560038
126 Treviño González JL, Reyes Suárez LL, Hernández de León JE. Malignant otitis externa: an updated review. Am J Otolaryngol. 2021;42(2):102894. doi:10.1016/j.amjoto.2020.102894 33429178
127 Gouzien L, Che D, Cassaing S, et al. Epidemiology and prognostic factors of mucormycosis in France (2012–2022): a cross-sectional study nested in a prospective surveillance programme. Lancet Reg Health Eur. 2024;45:101010. doi:10.1016/j.lanepe.2024.101010 39220434
128 Sharma A, Goel A. Mucormycosis: risk factors, diagnosis, treatments, and challenges during COVID-19 pandemic. Folia Microbiol (Praha). 2022;67(3):363-387. doi:10.1007/s12223-021-00934-5 35220559
129 Drogari-Apiranthitou M, Skiada A, Panayiotides I, et al. Epidemiology of mucormycosis in Greece; results from a nationwide prospective survey and published case reports. J Fungi (Basel). 2023;9(4):425. doi:10.3390/jof9040425 37108880
130 WHO fungal priority pathogens list to guide research, development, and public health action. Geneva: World Health Organization. 2022. Accessed January 30, 2026. https://www.who.int/publications/i/item/9789240060241
131 Skiada A, Pavleas I, Drogari-Apiranthitou M. Epidemiology and diagnosis of mucormycosis: an update. J Fungi (Basel). 2020;6(4):265. doi:10.3390/jof6040265 33147877
132 Corzo-León DE, Chora-Hernández LD, Rodríguez-Zulueta AP, Walsh TJ. Diabetes mellitus as the major risk factor for mucormycosis in Mexico: epidemiology, diagnosis, and outcomes of reported cases. Med Mycol. 2018;56(1):29-43. doi:10.1093/mmy/myx017 28431008
133 Bhansali A, Bhadada S, Sharma A, et al. Presentation and outcome of rhino-orbital-cerebral mucormycosis in patients with diabetes. Postgrad Med J. 2004;80(949):670-674. doi:10.1136/pgmj.2003.016030 15537854
134 Dong N, Jordan AE, Shen X, et al. Rhino-orbital cerebral mucormycosis in a patient with diabetic ketoacidosis: a case report and literature review. Front Neurol. 2022;13:815902. doi:10.3389/fneur.2022.815902 35599740
135 Jiménez-Jacinto JO, Montaño-Velázquez BB, Tirado-Sánchez A. Clinical characteristics and impact of glycemic control and antifungal treatment on mortality in patients with rhino-orbital mucormycosis in Mexico: a retrospective cohort study. medRxiv. 2025;doi:10.1101/2025.04.29.25326664
136 Mencarini L, Vestito A, Zagari RM, Montagnani M. The diagnosis and treatment of acute cholecystitis: a comprehensive narrative review for a practical approach. J Clin Med. 2024;13(9):2695. doi:10.3390/jcm13092695 38731224
137 Safwan M, Penny SM. Emphysematous cholecystitis: a deadly twist to a common disease. J Diagnostic Medical Sonography. 2016;32(3):131-137. doi:10.1177/8756479316631535
138 Chen MY, Lu C, Wang YF, Cai XJ. Emphysematous cholecystitis in a young male without predisposing factors: a case report. Medicine (Baltimore). 2016;95(44):e5367. doi:10.1097/MD.0000000000005367 27858922
139 Navarro-Torné A, Curcio D, Moïsi JC, Jodar L. Burden of invasive group B Streptococcus disease in non-pregnant adults: a systematic review and meta-analysis. PLoS One. 2021;16(9):e0258030. doi:10.1371/journal.pone.0258030 34591924
140 van Kassel MN, Janssen S, Kofman S, Brouwer MC, van de Beek D, Bijlsma MW. Prevalence of group B streptococcal colonization in the healthy non-pregnant population: a systematic review and meta-analysis. Clin Microbiol Infect. 2021;27(7):968-980. doi:10.1016/j.cmi.2021.03.024 33813109
141 Francois Watkins LK, McGee L, Schrag SJ, et al. Epidemiology of invasive group B streptococcal infections among nonpregnant adults in the United States, 2008–2016. JAMA Intern Med. 2019;179(4):479-488. doi:10.1001/jamainternmed.2018.7269 30776079
142 Al-Rifai RH, Pearson F, Critchley JA, Abu-Raddad LJ. Association between diabetes mellitus and active tuberculosis: a systematic review and meta-analysis. PLoS One. 2017;12(11):e0187967. doi:10.1371/journal.pone.0187967 29161276
143 Sun H, Saeedi P, Karuranga S, et al. IDF Diabetes Atlas: Global, regional and country-level diabetes prevalence estimates for 2021 and projections for 2045. Diabetes Res Clin Pract. 2022;183:109119. doi:10.1016/j.diabres.2021.109119 34879977
144 Global Tuberculosis Report 2024. Geneva: World Health Organization. 2024. Accessed January 30, 2026. https://www.who.int/teams/global-programme-on-tuberculosis-and-lung-health/tb-reports/global-tuberculosis-report-2024/tb-disease-burden/1-1-tb-incidence
145 Boadu AA, Yeboah-Manu M, Osei-Wusu S, Yeboah-Manu D. Tuberculosis and diabetes mellitus: the complexity of the comorbid interactions. Int J Infect Dis. 2024;146:107140. doi:10.1016/j.ijid.2024.107140 38885832
146 Kapur A, Harries AD. The double burden of diabetes and tuberculosis—public health implications. Diabetes Res Clin Pract. 2013;101(1):10-19. doi:10.1016/j.diabres.2012.12.001 23305899
147 Ferrara G, Murray M, Winthrop K, et al. Risk factors associated with pulmonary tuberculosis: smoking, diabetes and anti-TNFα drugs. Curr Opin Pulm Med. 2012;18(3):233-240. doi:10.1097/MCP.0b013e328351f9d6 22388583
148 Jeon CY, Harries AD, Baker MA, et al. Bi-directional screening for tuberculosis and diabetes: a systematic review. Trop Med Int Health. 2010;15(11):1300-1314. doi:10.1111/j.1365-3156.2010.02632.x 20958887
149 Jeon CY, Murray MB. Diabetes mellitus increases the risk of active tuberculosis: a systematic review of 13 observational studies. PLoS Med. 2008;5(7):e152. doi:10.1371/journal.pmed.0050152 18630984
150 Huang L-K, Wang H-H, Lai Y-C, Chang S-C. The impact of glycemic status on radiological manifestations of pulmonary tuberculosis in diabetic patients. PLoS One. 2017;12(6):e0179750. doi:10.1371/journal.pone.0179750 28628646
151 Gautam S, Shrestha N, Mahato S, Nguyen TPA, Mishra SR, Berg-Beckhoff G. Diabetes among tuberculosis patients and its impact on tuberculosis treatment in South Asia: a systematic review and meta-analysis. Sci Rep. 2021;11(1):2113. doi:10.1038/s41598-021-81057-2 33483542
152 Rehman AU, Khattak M, Mushtaq U, et al. The impact of diabetes mellitus on the emergence of multi-drug resistant tuberculosis and treatment failure in TB-diabetes comorbid patients: a systematic review and meta-analysis. Front Public Health. 2023;11:1244450. doi:10.3389/fpubh.2023.1244450 38074769
153 Tegegne BS, Mengesha MM, Teferra AA, Awoke MA, Habtewold TD. Association between diabetes mellitus and multi-drug-resistant tuberculosis: evidence from a systematic review and meta-analysis. Syst Rev. 2018;7(1):161. doi:10.1186/s13643-018-0828-0 30322409
154 Ragouraman D, Priyadharsini RP, Venkatesh C. Prevalence of tuberculosis and diabetes comorbidity in patients attending secondary healthcare hospital in south India: a retrospective study. J Family Med Prim Care. 2021;10(3):1241-1245. doi:10.4103/jfmpc.jfmpc_1984_20 34041158
155 World Health Organization and International Union against Tuberculosis and Lung Disease. Collaborative framework for care and control of tuberculosis and diabetes. World Health Organization. 2011. https://iris.who.int/handle/10665/44698
156 Nahid P, Dorman SE, Alipanah N, et al. Official American Thoracic Society/Centers for Disease Control and Prevention/Infectious Diseases Society of America Clinical Practice Guidelines: Treatment of Drug-Susceptible Tuberculosis. Clin Infect Dis. 2016;63(7):e147-e195. doi:10.1093/cid/ciw376 27516382
157 Daryabor G, Atashzar MR, Kabelitz D, Meri S, Kalantar K. The effects of type 2 diabetes mellitus on organ metabolism and the immune system. Front Immunol. 2020;11:1582. doi:10.3389/fimmu.2020.01582 32793223
158 Van Ende M, Wijnants S, Van Dijck P. Sugar sensing and signaling in Candida albicans and Candida glabrata. Front Microbiol. 2019;10:99. doi:10.3389/fmicb.2019.00099 30761119
159 d’Enfert C, Kaune AK, Alaban LR, et al. The impact of the fungus-host-microbiota interplay upon Candida albicans infections: current knowledge and new perspectives. FEMS Microbiol Rev. 2021;45(3):fuaa060. doi:10.1093/femsre/fuaa060 33232448
160 Cohen Atsmoni S, Brener A, Roth Y. Diabetes in the practice of otolaryngology. Diabetes Metab Syndr. 2019;13(2):1141-1150. doi:10.1016/j.dsx.2019.01.006 31336457
161 Maity S, Leton N, Nayak N, et al. A systematic review of diabetic foot infections: pathogenesis, diagnosis, and management strategies. Front Clin Diabetes Healthc. 2024;5:1393309. doi:10.3389/fcdhc.2024.1393309 39165660
162 Kostoglou-Athanassiou I, Athanassiou P, Gkountouvas A, Kaldrymides P. Vitamin D and glycemic control in diabetes mellitus type 2. Ther Adv Endocrinol Metab. 2013;4(4):122-128. doi:10.1177/2042018813501189 23997931
163 Buasroung P, Petnak T, Liwtanakitpipat P, Kiertiburanakul S. Prevalence of diabetes mellitus in patients with tuberculosis: a prospective cohort study. Int J Infect Dis. 2022;116:374-379. doi:10.1016/j.ijid.2022.01.047 35093530
164 Powell BJ, Waltz TJ, Chinman MJ, et al. A refined compilation of implementation strategies: results from the Expert Recommendations for Implementing Change (ERIC) project. Implement Sci. 2015;10:21. doi:10.1186/s13012-015-0209-1 25889199
165 The Joint Commission. Infection Prevention and Control and Antibiotic Stewardship. 2025. Accessed March 18, 2025. https://www.jointcommission.org/our-priorities/infection-prevention-and-control/
166 Chang C-H, Wang J-L, Wu L-C, Chuang L-M, Lin H-H. Diabetes, glycemic control, and risk of infection morbidity and mortality: a cohort study. Open Forum Infect Dis. 2019;6(10):ofz358. doi:10.1093/ofid/ofz358 31660337
167 Ooi YC, Dagi TF, Maltenfort M, et al. Tight glycemic control reduces infection and improves neurological outcome in critically ill neurosurgical and neurological patients. In: Database of Abstracts of Reviews of Effects (DARE): Quality-assessed Reviews [Internet]. Centre for Reviews and Dissemination (UK); 2012. https://www.ncbi.nlm.nih.gov/books/NBK109888/
168 Ernawati U, Wihastuti TA, Utami YW. Effectiveness of diabetes self-management education (DSME) in type 2 diabetes mellitus (T2DM) patients: systematic literature review. J Public Health Res. 2021;10(2):2240. doi:10.4081/jphr.2021.2240 33855427
169 Musuuza J, Sutherland BL, Kurter S, Balasubramanian P, Bartels CM, Brennan MB. A systematic review of multidisciplinary teams to reduce major amputations for patients with diabetic foot ulcers. J Vasc Surg. 2020;71(4):1433-1446.e3. doi:10.1016/j.jvs.2019.08.244 31676181
170 American Diabetes Association Professional Practice Committee for Diabetes. 1. Improving Care and Promoting Health in Populations: Standards of Care in Diabetes-2026. Diabetes Care. 2026;49(Supplement_1):S13-S26. doi:10.2337/dc26-S001 41358887
171 Wan EYF, Fung CSC, Jiao FF, et al. Five-year effectiveness of the multidisciplinary Risk Assessment and Management Programme-Diabetes Mellitus (RAMP-DM) on diabetes-related complications and health service uses-a population-based and propensity-matched cohort study. Diabetes Care. 2018;41(1):49-59. doi:10.2337/dc17-0426 29138274
172 Rosenfeld RM, Piccirillo JF, Chandrasekhar SS, et al. Clinical Practice Guideline (Update): Adult Sinusitis. Otolaryngol Head Neck Surg. 2015;152(2 Suppl):S1-S39. doi:10.1177/0194599815572097
173 Brook I. Microbiology of sinusitis. Proc Am Thorac Soc. 2011;8(1):90-100. doi:10.1513/pats.201006-038RN 21364226
174 Wenzel RP, Fowler AA, 3rd. Clinical practice. Acute bronchitis. N Engl J Med. 2006;355(20):2125-2130. doi:10.1056/NEJMcp061493 17108344
175 Albert RH. Diagnosis and treatment of acute bronchitis. Am Fam Physician. 2010;82(11):1345-1350. https://www.aafp.org/pubs/afp/issues/2010/1201/p1345.html 21121518
176 Centers for Disease Control and Prevention. National Center for Health Statistics—ICD-10-CM. 2024. https://icd10cmtool.cdc.gov/?fy=FY2024

FIGURE 1.

Percentage of Deaths Caused by Infection, by Diabetes Status and Infection Type, U.S., 1999–2023.

Diabetes status and infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). HIV, human immunodeficiency virus.

* Any infection among those included in this figure

SOURCE: National Vital Statistics System 1999–2023

Line graphs showing that the percent of deaths caused by infections remained stable between 1999 and 2023, except for an increase in respiratory infections in 2021 and 2022, regardless of diabetes status.

FIGURE 2.

Age-Standardized Percentage of Hospital Discharges Listing Infection, by Diabetes Status and Infection Type, U.S., 1999–2021.

Diabetes status and infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years. HIV, human immunodeficiency virus.

* Any infection among those included in this figure

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graphs showing that the percent of hospital discharges for skin and connective tissue infections was consistently higher for those with diabetes compared to those without diabetes between 1999 and 2021.

FIGURE 3.

Age-Standardized Percentage of Hospital Discharges Listing Any Infection, by Diabetes Status, U.S., 1999–2021.

Diabetes status and infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for any infection was higher for those with diabetes compared to those without diabetes and both groups showed a gradual increase for infection related hospital discharges between 1999 and 2021.

FIGURE 4.

Age-Standardized Percentage of Hospital Discharges Listing Respiratory Tract Infections, by Diabetes Status, U.S., 1999–2021.

Diabetes status and respiratory tract infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for respiratory infections was similar by diabetes status between 1999 and 2019 but was higher for those with diabetes in 2020 and 2021.

FIGURE 5.

Age-Standardized Percentage of Hospital Discharges Listing Urinary Tract Infections, by Diabetes Status, U.S., 1999–2021.

Diabetes status and urinary tract infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for urinary tract infections was similar by diabetes status between 1999 and 2015 but was higher for those with diabetes in 2016 through 2021.

FIGURE 6.

Age-Standardized Percentage of Hospital Discharges Listing Skin and Connective Tissue Infections, by Diabetes Status, U.S., 1999–2021.

Diabetes status and skin and connective tissue infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for skin and connective tissue infections was about 10 percent for adults with diabetes and around 3 percent for adults without diabetes between 1999 and 2021.

FIGURE 7.

Age-Standardized Percentage of Hospital Discharges Listing Hospital-Acquired Infections, by Diabetes Status, U.S., 1999–2021.

Diabetes status and hospital-acquired infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for hospital-acquired infections was higher for those with diabetes compared to those without diabetes and increased from 4 percent in 1999 to 7 and a half percent in 2021 for those with diabetes.

FIGURE 8.

Age-Standardized Percentage of Outpatient Visits to a Physician Pertaining to Infections, by Diabetes Status, U.S., 1999–2019.

Diabetes status and infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age-standardized to the NAMCS 1999–2016, 2018–2019, using age groups 0–44, 45–64, and ≥65 years. All relative standard errors >30% indicated in the graph pertain to outpatient visits among persons with diabetes; relative standard errors are ≤30% for all data among persons without diabetes.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Ambulatory Medical Care Surveys (NAMCS) 1999–2019

Line graph showing the percent of outpatient visits pertaining to infections ranged from 1 percent to 5 percent between 1999 and 2019 for adults with diabetes and between 2 and 3 percent for those without diabetes.

FIGURE 9.

Age-Standardized Percentage of Hospital Discharges Listing Influenza, by Diabetes Status, U.S., 1999–2021.

Diabetes status and influenza are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for influenza increased slightly from 1999 to 2015 but decreased between 2015 and 2021, regardless of diabetes status.

FIGURE 10.

Age-Standardized Percentage of Hospital Discharges Listing Sinusitis and Bronchitis, by Diabetes Status, U.S., 1999–2021.

Diabetes status and sinusitis and bronchitis are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing that the percent of hospital discharges for sinusitis and bronchitis was stable between 1999 and 2015 and then decreased between 2015 and 2021, regardless of diabetes status.

FIGURE 11.

Age-Standardized Percentage of Hospital Discharges Listing COVID-19, by Diabetes Status, U.S., 2019–2021.

Diabetes status and COVID-19 are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years. COVID-19, coronavirus disease of 2019.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 2019–2021

Line graph showing the percent of hospital discharges for COVID 19 was higher for those with diabetes than without diabetes in 2020 and 2021 with 10 percent of hospital discharges listing COVID 19 in 2021 for those with diabetes.

FIGURE 12.

Age-Standardized Percentage of Hospital Discharges Listing Sepsis, by Diabetes Status, U.S., 1999–2021.

Diabetes status and sepsis are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges for sepsis gradually increased between 1999 and 2021 regardless of diabetes status but the percent of discharges was higher for those with diabetes.

FIGURE 13.

Age-Standardized Percentage of Hospital Discharges Listing Oral and Vaginal Candidiasis, by Diabetes Status, U.S., 1999–2021.

Diabetes status and oral and vaginal candidiasis are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges for oral and vaginal candidiasis was higher for those with diabetes compared to those without diabetes between 1999 and 2021 with 0.6 percent of discharges among those with diabetes listing the conditions in 2021.

FIGURE 14.

Age-Standardized Percentage of Hospital Discharges Listing Cellulitis and Impetigo, by Diabetes Status, U.S., 1999–2021.

Diabetes status and cellulitis and impetigo are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges listing cellulitis and impetigo were two times higher for those with diabetes compared to those without diabetes between 1999 and 2021 with 6 percent of discharges among those with diabetes listing the conditions in 2021.

FIGURE 15.

Age-Standardized Percentage of Hospital Discharges Listing Foot Ulcers, by Diabetes Status, U.S., 1999–2021.

Diabetes status and foot ulcers are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges listing foot ulcers was significantly higher for those with diabetes compared to those without diabetes between 1999 and 2021 with 4 percent of discharges among those with diabetes listing the condition in 2021.

FIGURE 16.

Age-Standardized Percentage of Hospital Discharges Listing Osteomyelitis, by Diabetes Status, U.S., 1999–2021.

Diabetes status and osteomyelitis are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges listing osteomyelitis was higher for those with diabetes compared to those without diabetes between 1999 and 2021 with nearly 1 percent of discharges among those with diabetes listing the condition in 2021.

FIGURE 17.

Age-Standardized Percentage of Hospital Discharges Listing Fournier’s Gangrene, by Diabetes Status, U.S., 1999–2021.

Diabetes status and Fournier’s gangrene are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges listing gangrene was significantly higher for those with diabetes compared to those without diabetes between 1999 and 2021 with 0.8 percent of discharges among those with diabetes listing the condition in 2021.

FIGURE 18.

Mortality Among Patients With Hospital-Acquired Infections, by Diabetes Status, U.S., 1999–2023.

Diabetes status and hospital-acquired infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1).

SOURCE: National Vital Statistics System 1999–2023

Line graph showing that mortality among patients with hospital acquired infections was higher for those without diabetes compared to those with diabetes between 1999 and 2023.

FIGURE 19.

Age-Standardized Percentage of Hospital Discharges Listing Postoperative Wound Infections, by Diabetes Status, U.S., 1999–2021.

Diabetes status and postoperative wound infections are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges for postoperative wound infections was stable between 1999 and 2021 but higher for those with diabetes compared to those without diabetes.

FIGURE 20.

Age-Standardized Percentage of Hospital Discharges Listing Emphysematous Cholecystitis, by Diabetes Status, U.S., 1999–2021.

Diabetes status and emphysematous cholecystitis are defined by International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years.

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

Line graph showing the percent of hospital discharges listing emphysematous cholecystitis was similar for those with and without diabetes between 1999 and 2021.

TABLE 1.

Summary of Infections Associated With Diabetes

INFECTION (REF.) | COMMON PATHOGENS | CLINICAL FEATURES | DIAGNOSIS
Respiratory Tract Infections
Influenza | Influenza A, Influenza B | Fever, malaise, myalgia, nonproductive cough | NAAT, RT-PCR
Pneumonia | Staphylococcus aureus, Streptococcus pneumoniae, Haemophilus influenzae, various other gram-negative rods, and atypical pathogens | Fever, malaise, myalgia, nonproductive cough | Chest radiography, sputum culture
Invasive pneumococcal disease | Streptococcus pneumoniae | Fever, site-specific symptoms (e.g., headache and neck stiffness in meningitis, chest pain in empyema, joint pain in septic arthritis) | Urinary antigen, blood culture, CSF culture, pleural fluid culture, synovial fluid culture
Sinusitis (172,173) | [underlined: Viral]: rhinovirus, adenovirus, RSV, influenza, and parainfluenza [underlined: Bacterial]: Streptococcus pneumoniae, Haemophilus influenzae, Moraxella catarrhalis | Fever, headache, cough, nasal discharge, facial pain and swelling, sore throat | Clinical diagnosis, CT/MR imaging for complications
Bronchitis (174,175) | [underlined: Viral (common)]: influenza, parainfluenza, rhinoviruses, and SARS-CoV-2 [underlined: Bacterial]: Bordetella pertussis, Mycoplasma pneumoniae, Chlamydia pneumoniae | Cough, wheezing, headache, nasal congestion, sore throat | Clinical diagnosis, chest radiography
COVID-19 | SARS-CoV-2 | Wide spectrum from asymptomatic to critical illness | Clinical diagnosis, RAT, NAAT, RT-PCR
Urinary Tract Infections
Asymptomatic bacteriuria | Escherichia coli, Proteus species, Staphylococcus saprophyticus, Klebsiella, Enterococci | Asymptomatic | Urine analysis and culture
Cystitis | Escherichia coli, Proteus species | Dysuria, increased urinary frequency, urinary urgency, suprapubic pain | Urine analysis and culture
Pyelonephritis | Escherichia coli, Proteus species, Staphylococcus saprophyticus, Klebsiella, Enterococci | Flank pain, fever, chills, dysuria, increased urinary frequency, urinary urgency, suprapubic pain | Urine analysis and culture
Emphysematous pyelonephritis | Escherichia coli, Klebsiella pneumoniae, Proteus | Flank or abdominal pain, fever, nausea | CT, plain radiography
Perinephric abscess | Gram-negative enteric bacilli, polymicrobial, Staphylococcus aureus | Flank pain, fever | Plain radiography, ultrasound, or CT
Skin and Connective Tissue Infections
Oral and vaginal candidiasis; intertrigo | Candida albicans | Thrush, rash, discharge | Clinical diagnosis, microscopic examination, culture
Onychomycosis | Trichophyton rubrum, Trichophyton mentagrophytes | Nail discoloration | Clinical diagnosis
Cellulitis and impetigo | Staphylococcus aureus, Staphylococcus pyogenes | Redness, pain, skin lesion | Clinical diagnosis
Foot ulcers | • Cellulitis without an open skin wound: β-hemolytic Streptococcus and Staphylococcus aureus • Infected ulcer and antibiotic naïve: Staphylococcus aureus and β-hemolytic Streptococcus • Chronic infected ulcer or was previously treated with antibiotics: Staphylococcus aureus, β-hemolytic Streptococcus, Enterobacteriaceae • Macerated ulcer (due to soaking): Pseudomonas aeruginosa (often with other organisms) • Long-duration nonhealing ulcer with prolonged antibiotic therapy: aerobic gram-positive cocci, diphtheroids, Enterobacteriaceae, Pseudomonas species, fungi • Extensive necrosis and gangrene: mixed aerobic gram-positive cocci, Enterobacteriaceae, non-fermenting gram-negative rods, obligate anaerobes | See Table 3. | Clinical examination, radiology, CT, culture
Osteomyelitis | See “Foot ulcers” | Chronic, nonhealing ulcers, leukocytosis, fever | Radiology, MR imaging, radioisotope scans, bone biopsy
Necrotizing fasciitis or Fournier’s gangrene | Gram-negative rods, anaerobes (type 1) or group A Streptococci | Pain, redness, crepitus, skin lesion | Radiology, CT
Other Infections Associated With Diabetes
Necrotizing otitis externa | Pseudomonas aeruginosa, methicillin-resistant Staphylococcus aureus (MRSA), Proteus mirabilis, Klebsiella spp., Aspergillus fumigatus | Ear pain, hearing loss, cellulitis, discharge | Clinical examination, MR imaging
Mucormycosis | Mucor and Rhizopus species | Facial or ocular pain, fever, black nasal eschar | Clinical examination, MR imaging, pathology
Emphysematous cholecystitis | Gram-negative bacilli, anaerobes, most commonly polymicrobial | Right upper quadrant abdominal pain, fever, systemic toxicity | Radiology, CT
Group B streptococcal infections | Streptococcus agalactiae | Skin and soft tissue (cellulitis, abscess, necrotizing fasciitis, sternal wound infections), bacteremia without clear cause, urinary tract (cystitis, pyelonephritis), pneumonia, osteomyelitis, septic arthritis, endocarditis, meningitis | Culture

COVID-19, coronavirus disease of 2019; CSF, cerebrospinal fluid; CT, computed tomography; MR, magnetic resonance; NAAT, Nucleic Acid Amplification Test; RAT, rapid antigen testing; RSV, respiratory syncytial virus; RT-PCR, reverse transcription polymerase chain reaction; SARS-CoV-2, severe acute respiratory syndrome coronavirus 2.

SOURCE: References are listed within the table.

TABLE 2.

Vaccine Recommendations for Patients With Diabetes

INFECTION | ADVISORY COMMITTEE ON IMMUNIZATION PRACTICES (ACIP) RECOMMENDATIONS
Influenza | • Annual vaccination (starting in September) for all individuals with diabetes age ≥6 months. • Dosage and vaccine type are based on the patient’s age and comorbidities. • Caution is advised when administering the live-attenuated influenza vaccine (LAIV) to individuals with diabetes.
Respiratory syncytial virus (RSV) | • One dose of RSV vaccine is recommended for all individuals age ≥75 years. • One dose of RSV vaccine is recommended for individuals age ≥60 years with diabetes and end-organ damage (e.g., diabetic nephropathy, neuropathy, retinopathy, or cardiovascular disease) or requiring treatment with insulin or a sodium-glucose cotransporter-2 (SGLT) inhibitor.
Streptococcus pneumoniae | • Recommended for all adults age ≥50 years and adults age 19–49 years with diabetes: o Option 1: Pneumococcal conjugate vaccine 20 (PCV-20) alone o Option 2: PCV-15 followed by pneumococcal polysaccharide vaccine 23 (PPSV-23) after 1 year
COVID-19 | • Recommended for all individuals with diabetes age ≥6 months. • Dose and vaccine type depend on the patient’s age and immunocompromising conditions. • Vaccines should be effective against recent circulating strains.

The most recent U.S. vaccine guidelines should be confirmed through the Centers for Disease Control and Prevention’s Advisory Committee on Immunization Practices (ACIP) (https://www.cdc.gov/acip/index.html). COVID-19, coronavirus disease of 2019; PCV, pneumococcal conjugate vaccine; RSV, respiratory syncytial virus.

SOURCE: References (24,28,33,52)

TABLE 3.

Classification of Diabetic Foot Infections

WAGNER CLASSIFICATION, 1983 | INFECTIOUS DISEASES SOCIETY OF AMERICA (IDSA) CLASSIFICATION, 2012 | PEDIS* GRADE
Grade 0: No ulcer in high-risk foot Grade 1: Superficial ulcer involving the full skin thickness but no underlying tissue Grade 2: Deep ulcer penetrating down to ligaments and muscle, but no bone involvement or abscess formation Grade 3: Deep ulcer with cellulitis or abscess formation, often with osteomyelitis Grade 4: Localized gangrene Grade 5: Extensive gangrene involving the whole foot | Uninfected: Wound lacking purulence or any manifestations of inflammation Mild: Presence of ≥2 manifestations of inflammation (purulence, erythema, pain, tenderness, warmth, induration), but any cellulitis/erythema extends ≤2 cm around the ulcer, and infection is limited to the skin and subcutaneous tissues; no other complications or systemic illness. Moderate: Presence of ≥1 of these characteristics: cellulitis extending >2 cm, lymphangitis streaking, spread beneath the superficial fascia, deep tissue abscess, gangrene, and involvement of muscle, tendon, joint, or bone. Patient is systemically well and metabolically stable. Severe: Infection in patients with systemic toxicity or metabolic instability. | PEDIS – perfusion, extent/size, depth/tissue loss, infection, sensation based on IDSA classification 1 (uninfected) 2 (mild) 3 (moderate) 4 (severe)

* The PEDIS (Perfusion, Extent, Depth, Infection, and Sensation) classification system was developed by the International Working Group on the Diabetic Foot (IWGDF).

SOURCE: Reference (86,87)

## Appendices

APPENDIX TABLE A1.

List of ICD-9 and ICD-10 Codes Used in This Article

INFECTION | ICD-9 CODES | ICD-10 CODES
Respiratory Tract Infections
Influenza | 480–488 | J10.1, J18.9
Sinusitis and bronchitis | 461, 466 | J32.9, J40
COVID-19 | NA | U07.1, B97.2
Urinary Tract Infections
Asymptomatic bacteriuria | 791.9 | N39.0
Cystitis | 595 | N30.9
Pyelonephritis | 590.1, 590.8 | N10
Perinephric abscess | 590.2 | N15.1
Skin and Connective Tissue Infections
Oral and vaginal candidiasis | 112.0–112.3 | B37.0, B37.3
Onychomycosis | 110.1 | B35.1
Intertrigo and erythematous conditions | 695.89 | L26, L30.4, L53.8, L92.0, L95.1, L98.2
Cellulitis and impetigo | 682, 684 | L03, L01
Foot ulcers | 707.1 | L97
Osteomyelitis | 730.2 | M86.9
Necrotizing fasciitis | 728.86 | M72.6
Gangrene | 785.4 | I96
Hospital-Acquired Infections
Sepsis | 38 | A41.9
Postoperative wound infections | 998.59 | T81.49
Other Infections Associated With Diabetes
Necrotizing otitis externa | 380.14 | H60.2
Mucormycosis | 117.7 | B46.5
Emphysematous cholecystitis | 575 | K81.0
Other
Tuberculosis | 010–018 | A15.9
HIV | 042–044 | B20
Diabetes | 250, 357.2, 362.0, 366.41, 648.0, 775.1 | E10–E14

The transition from ICD-9 to ICD-10 coding occurred in late 2015. COVID-19, coronavirus disease of 2019; HIV, human immunodeficiency virus; ICD-9/10, International Classification of Diseases, Ninth/Tenth Revision; NA, not applicable.

SOURCE: Reference (176)

APPENDIX TABLE A2.

Percentage of Deaths Caused by Infections, by Diabetes Status and Infection Type, U.S., 1999–2023

YEAR | PERCENT
YEAR | Diabetes | | | | | | | No Diabetes
YEAR | Any Infection* | Respiratory Tract Infections | Urinary Tract Infections | Skin And Connective Tissue Infections | Hospital-Acquired Infections | Other Infections Associated With Diabetes | HIV | Any Infection* | Respiratory Tract Infections | Urinary Tract Infections | Skin And Connective Tissue Infections | Hospital-Acquired Infections | Other Infections Associated With Diabetes | HIV
1999 | 3.10 | 1.27 | 0.67 | 0.16 | 0.93 | 0.03 | 0.04 | 4.50 | 2.39 | 0.59 | 0.06 | 1.17 | 0.03 | 0.27
2000 | 3.16 | 1.35 | 0.65 | 0.17 | 0.92 | 0.03 | 0.04 | 4.53 | 2.41 | 0.58 | 0.07 | 1.19 | 0.03 | 0.26
2001 | 3.26 | 1.36 | 0.65 | 0.18 | 0.98 | 0.04 | 0.05 | 4.49 | 2.33 | 0.58 | 0.08 | 1.23 | 0.03 | 0.25
2002 | 3.38 | 1.43 | 0.64 | 0.20 | 1.02 | 0.05 | 0.05 | 4.63 | 2.43 | 0.57 | 0.08 | 1.28 | 0.03 | 0.25
2003 | 3.33 | 1.35 | 0.65 | 0.24 | 1.00 | 0.04 | 0.06 | 4.60 | 2.37 | 0.57 | 0.10 | 1.30 | 0.03 | 0.23
2004 | 3.23 | 1.26 | 0.66 | 0.25 | 0.97 | 0.04 | 0.05 | 4.51 | 2.24 | 0.58 | 0.11 | 1.31 | 0.04 | 0.23
2005 | 3.35 | 1.31 | 0.68 | 0.25 | 1.02 | 0.04 | 0.05 | 4.55 | 2.29 | 0.61 | 0.10 | 1.30 | 0.04 | 0.21
2006 | 3.17 | 1.19 | 0.67 | 0.26 | 0.96 | 0.04 | 0.06 | 4.35 | 2.09 | 0.60 | 0.11 | 1.32 | 0.03 | 0.20
2007 | 3.10 | 1.14 | 0.65 | 0.26 | 0.96 | 0.04 | 0.05 | 4.30 | 2.02 | 0.60 | 0.11 | 1.35 | 0.04 | 0.18
2008 | 2.85 | 1.14 | 0.42 | 0.25 | 0.95 | 0.04 | 0.04 | 4.21 | 2.07 | 0.46 | 0.10 | 1.37 | 0.04 | 0.17
2009 | 2.79 | 1.09 | 0.42 | 0.25 | 0.93 | 0.05 | 0.04 | 4.08 | 1.93 | 0.45 | 0.11 | 1.38 | 0.04 | 0.16
2010 | 2.70 | 1.00 | 0.41 | 0.25 | 0.95 | 0.04 | 0.04 | 3.96 | 1.87 | 0.45 | 0.12 | 1.34 | 0.04 | 0.13
2011 | 2.76 | 1.07 | 0.42 | 0.28 | 0.90 | 0.04 | 0.05 | 4.04 | 1.94 | 0.46 | 0.12 | 1.36 | 0.04 | 0.12
2012 | 2.63 | 0.99 | 0.39 | 0.28 | 0.89 | 0.04 | 0.03 | 3.91 | 1.83 | 0.45 | 0.12 | 1.35 | 0.04 | 0.11
2013 | 2.62 | 1.02 | 0.38 | 0.21 | 0.92 | 0.04 | 0.04 | 4.06 | 1.93 | 0.45 | 0.13 | 1.41 | 0.04 | 0.10
2014 | 2.50 | 0.93 | 0.39 | 0.22 | 0.88 | 0.04 | 0.04 | 4.00 | 1.82 | 0.46 | 0.14 | 1.44 | 0.04 | 0.10
2015 | 2.52 | 0.89 | 0.40 | 0.25 | 0.90 | 0.05 | 0.04 | 4.02 | 1.82 | 0.46 | 0.15 | 1.46 | 0.05 | 0.09
2016 | 2.43 | 0.81 | 0.39 | 0.24 | 0.90 | 0.05 | 0.03 | 3.81 | 1.65 | 0.46 | 0.15 | 1.42 | 0.05 | 0.09
2017 | 2.45 | 0.87 | 0.37 | 0.25 | 0.87 | 0.05 | 0.02 | 3.78 | 1.64 | 0.44 | 0.16 | 1.42 | 0.05 | 0.07
2018 | 2.44 | 0.86 | 0.37 | 0.26 | 0.87 | 0.05 | 0.03 | 3.73 | 1.63 | 0.43 | 0.16 | 1.40 | 0.05 | 0.07
2019 | 2.29 | 0.76 | 0.37 | 0.28 | 0.80 | 0.05 | 0.02 | 3.45 | 1.43 | 0.41 | 0.17 | 1.32 | 0.05 | 0.07
2020 | 16.57 | 15.25 | 0.32 | 0.24 | 0.69 | 0.04 | 0.02 | 12.92 | 11.10 | 0.39 | 0.16 | 1.17 | 0.05 | 0.06
2021 | 16.77 | 15.31 | 0.36 | 0.30 | 0.74 | 0.05 | 0.02 | 14.58 | 12.72 | 0.41 | 0.17 | 1.18 | 0.05 | 0.05
2022 | 8.55 | 6.91 | 0.39 | 0.32 | 0.85 | 0.06 | 0.03 | 8.75 | 6.73 | 0.45 | 0.19 | 1.27 | 0.05 | 0.05
2023 | 3.97 | 2.20 | 0.42 | 0.33 | 0.93 | 0.06 | 0.03 | 4.88 | 2.79 | 0.45 | 0.21 | 1.32 | 0.06 | 0.05

Diabetes status and infections are defined based on International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). HIV, human immunodeficiency virus.

* Any infection among those listed in this table.

SOURCE: National Vital Statistics System 1999–2023

APPENDIX TABLE A3.

Age-Standardized Percentage of Hospital Discharges Listing Infection, by Diabetes Status and Infection Type, U.S., 1999–2021

TYPE OF INFECTION | PERCENT (STANDARD ERROR)
TYPE OF INFECTION | 1999 | 2000 | 2001 | 2002 | 2003 | 2004 | 2005 | 2006 | 2007 | 2008 | 2009 | 2010 | 2011 | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019 | 2020 | 2021
Diabetes
Any infection (among those listed below) | 20.5 (0.16) | 19.7 (0.16) | 19.5 (0.16) | 19.9 (0.15) | 20.6 (0.16) | 20.6 (0.17) | 21.5 (0.19) | 21.3 (0.18) | 21.7 (0.16) | 22.3 (0.18) | 22.8 (0.17) | 22.5 (0.19) | 23.7 (0.19) | 23.6 (0.09) | 24.5 (0.10) | 25.3 (0.10) | 25.9 (0.11) | 28.2 (0.12) | 28.4 (0.12) | 28.8 (0.12) | 27.9 (0.12) | 34.1 (0.14) | 34.9 (0.15)
Respiratory tract infections
Any | 7.9 (0.08) | 7.2 (0.08) | 7.0 (0.08) | 7.2 (0.08) | 7.8 (0.09) | 7.5 (0.09) | 8.2 (0.09) | 7.8 (0.10) | 8.1 (0.09) | 8.6 (0.10) | 9.0 (0.10) | 8.2 (0.11) | 8.6 (0.10) | 8.4 (0.05) | 8.9 (0.06) | 8.8 (0.05) | 9.0 (0.06) | 6.7 (0.05) | 6.8 (0.05) | 6.6 (0.05) | 5.6 (0.05) | 13.7 (0.10) | 14.9 (0.04)
Influenza | 6.7 (0.08) | 6.3 (0.08) | 6.1 (0.08) | 6.4 (0.07) | 6.9 (0.08) | 6.6 (0.08) | 7.3 (0.09) | 7.0 (0.09) | 7.2 (0.09) | 7.7 (0.09) | 8.0 (0.10) | 7.4 (0.10) | 7.8 (0.10) | 7.6 (0.05) | 8.1 (0.05) | 8.1 (0.05) | 8.3 (0.05) | 6.2 (0.05) | 6.3 (0.05) | 6.2 (0.05) | 5.2 (0.04) | 5.6 (0.05) | 4.7 (0.09)
Sinusitis and bronchitis | 1.3 (0.03) | 1.0 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 1.0 (0.03) | 1.0 (0.02) | 1.0 (0.02) | 0.9 (0.03) | 0.9 (0.02) | 1.1 (0.03) | 1.1 (0.03) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.01) | 0.9 (0.01) | 0.8 (0.01) | 0.9 (0.02) | 0.6 (0.01) | 0.6 (0.01) | 0.5 (0.01) | 0.5 (0.01) | 0.3 (0.01) | 0.2 (0.01)
COVID-19 | | | | | | | | | | | | | | | | | | | | | 0.1 (0.00) | 7.9 (0.08) | 10.1 (0.07)
Urinary tract infections
Any | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 1.0 (0.02) | 1.0 (0.02) | 1.0 (0.02) | 1.0 (0.03) | 1.1 (0.03) | 1.2 (0.03) | 1.3 (0.03) | 1.4 (0.02) | 1.4 (0.02) | 1.5 (0.02) | 1.7 (0.02) | 9.8 (0.06) | 9.3 (0.06) | 9.0 (0.07) | 8.4 (0.06) | 8.2 (0.06) | 8.1 (0.06)
Asymptomatic bacteriuria | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 9.0 (0.06) | 8.4 (0.06) | 8.2 (0.06) | 7.6 (0.06) | 7.4 (0.06) | 7.3 (0.06)
Cystitis | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.3 (0.01)
Pyelonephritis | 0.8 (0.02) | 0.7 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 1.0 (0.02) | 1.1 (0.03) | 1.1 (0.02) | 1.1 (0.02) | 1.2 (0.02) | 1.3 (0.02) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01)
Perinephric abscess | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00)
Skin and connective tissue infections
Any | 9.6 (0.10) | 9.5 (0.10) | 9.7 (0.11) | 9.8 (0.11) | 10.0 (0.10) | 10.2 (0.10) | 10.4 (0.12) | 10.6 (0.11) | 10.7 (0.10) | 10.6 (0.11) | 10.7 (0.09) | 11.0 (0.10) | 11.5 (0.12) | 11.4 (0.06) | 11.7 (0.06) | 12.1 (0.06) | 12.2 (0.07) | 10.5 (0.06) | 10.6 (0.06) | 11.2 (0.06) | 11.4 (0.07) | 10.8 (0.06) | 10.7 (0.06)
Oral and vaginal candidiasis | 1.2 (0.03) | 1.1 (0.02) | 1.2 (0.03) | 1.2 (0.03) | 1.2 (0.03) | 1.2 (0.03) | 1.3 (0.03) | 1.2 (0.03) | 1.3 (0.03) | 1.4 (0.03) | 1.5 (0.03) | 1.5 (0.03) | 1.5 (0.03) | 1.6 (0.02) | 1.5 (0.02) | 1.6 (0.02) | 1.5 (0.02) | 0.8 (0.01) | 0.8 (0.01) | 0.8 (0.01) | 0.8 (0.01) | 0.8 (0.01) | 0.7 (0.01)
Onychomycosis | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.1 (0.01) | 0.2 (0.01)
Intertrigo and erythematous conditions | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00)
Cellulitis and impetigo | 5.2 (0.06) | 5.4 (0.07) | 5.4 (0.07) | 5.6 (0.08) | 5.7 (0.07) | 6.0 (0.07) | 6.3 (0.09) | 6.3 (0.08) | 6.5 (0.07) | 6.4 (0.08) | 6.4 (0.07) | 6.6 (0.08) | 6.9 (0.09) | 7.0 (0.05) | 7.1 (0.05) | 7.3 (0.05) | 7.4 (0.05) | 6.9 (0.05) | 7.0 (0.05) | 7.1 (0.06) | 7.3 (0.06) | 6.8 (0.05) | 6.7 (0.05)
Foot ulcers | 3.3 (0.06) | 3.3 (0.06) | 3.6 (0.07) | 3.5 (0.06) | 3.5 (0.06) | 3.6 (0.06) | 3.5 (0.06) | 3.7 (0.06) | 3.6 (0.06) | 3.5 (0.05) | 3.4 (0.05) | 3.5 (0.06) | 3.8 (0.06) | 3.7 (0.04) | 4.0 (0.04) | 4.2 (0.04) | 4.3 (0.04) | 3.9 (0.04) | 4.1 (0.04) | 4.4 (0.04) | 4.7 (0.04) | 4.4 (0.04) | 4.4 (0.04)
Osteomyelitis | 0.8 (0.02) | 0.8 (0.03) | 0.8 (0.02) | 0.8 (0.03) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.03) | 1.0 (0.03) | 1.1 (0.03) | 1.2 (0.03) | 1.3 (0.03) | 1.3 (0.03) | 1.5 (0.04) | 1.4 (0.02) | 1.6 (0.02) | 1.7 (0.02) | 1.7 (0.02) | 0.8 (0.01) | 0.8 (0.01) | 0.9 (0.02) | 1.0 (0.02) | 1.0 (0.02) | 1.0 (0.02)
Necrotizing fasciitis | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.3 (0.01) | 0.3 (0.01)
Fournier’s gangrene | 1.1 (0.03) | 1.0 (0.03) | 1.0 (0.03) | 0.9 (0.02) | 0.9 (0.03) | 0.9 (0.03) | 0.8 (0.02) | 0.8 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.8 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.8 (0.01) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.01)
Hospital-acquired infections
Any | 3.8 (0.06) | 3.5 (0.06) | 3.5 (0.06) | 3.6 (0.07) | 3.7 (0.07) | 3.8 (0.08) | 3.8 (0.09) | 4.1 (0.09) | 4.4 (0.08) | 4.7 (0.09) | 4.9 (0.09) | 5.1 (0.10) | 5.7 (0.12) | 6.0 (0.05) | 6.8 (0.06) | 7.6 (0.07) | 8.5 (0.07) | 7.1 (0.07) | 7.8 (0.07) | 8.2 (0.07) | 8.3 (0.08) | 8.3 (0.07) | 8.1 (0.07)
Sepsis | 3.0 (0.06) | 2.8 (0.06) | 2.8 (0.06) | 2.8 (0.07) | 2.9 (0.07) | 3.0 (0.08) | 3.0 (0.09) | 3.3 (0.09) | 3.6 (0.08) | 3.9 (0.10) | 4.2 (0.09) | 4.4 (0.10) | 5.0 (0.12) | 5.4 (0.05) | 6.2 (0.06) | 7.0 (0.07) | 7.9 (0.07) | 6.5 (0.07) | 7.2 (0.07) | 7.6 (0.08) | 7.7 (0.08) | 7.7 (0.07) | 7.5 (0.07)
Postoperative wound infections | 0.8 (0.03) | 0.8 (0.02) | 0.8 (0.02) | 0.9 (0.02) | 0.9 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01)
Other infections associated with diabetes
Any | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.00)
Necrotizing otitis externa | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
Mucormycosis | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
Emphysematous cholecystitis | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00)
Other
Tuberculosis | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.01) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.01) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
HIV | 0.5 (0.05) | 0.5 (0.04) | 0.4 (0.04) | 0.4 (0.03) | 0.4 (0.03) | 0.4 (0.04) | 0.4 (0.03) | 0.5 (0.04) | 0.4 (0.03) | 0.4 (0.03) | 0.4 (0.03) | 0.4 (0.04) | 0.3 (0.03) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01)
No Diabetes
Any infection (among those listed below) | 13.2 (0.14) | 12.4 (0.13) | 12.2 (0.13) | 12.8 (0.13) | 13.5 (0.13) | 13.6 (0.14) | 14.6 (0.15) | 14.3 (0.14) | 14.5 (0.14) | 15.2 (0.14) | 15.6 (0.14) | 15.7 (0.15) | 16.0 (0.14) | 16.0 (0.07) | 16.6 (0.07) | 17.0 (0.08) | 12.1 (0.06) | 19.1 (0.08) | 18.9 (0.08) | 18.9 (0.09) | 18.1 (0.08) | 22.1 (0.10) | 23.4 (0.10)
Respiratory tract infections
Any | 7.8 (0.09) | 7.1 (0.09) | 6.7 (0.09) | 7.1 (0.09) | 7.6 (0.10) | 7.4 (0.09) | 8.0 (0.10) | 7.6 (0.09) | 7.7 (0.10) | 8.2 (0.10) | 8.4 (0.11) | 8.1 (0.11) | 8.3 (0.10) | 8.1 (0.05) | 8.5 (0.05) | 8.4 (0.05) | 6.0 (0.04) | 6.0 (0.04) | 6.1 (0.04) | 5.9 (0.04) | 5.1 (0.04) | 10.0 (0.07) | 11.4 (0.07)
Influenza | 6.6 (0.08) | 6.2 (0.07) | 5.8 (0.08) | 6.2 (0.08) | 6.6 (0.08) | 6.4 (0.08) | 7.1 (0.09) | 6.7 (0.08) | 6.9 (0.09) | 7.3 (0.09) | 7.5 (0.09) | 7.2 (0.09) | 7.5 (0.09) | 7.3 (0.04) | 7.7 (0.05) | 7.7 (0.05) | 5.4 (0.03) | 5.6 (0.04) | 5.6 (0.04) | 5.5 (0.04) | 4.6 (0.04) | 5.0 (0.04) | 4.3 (0.03)
Sinusitis and bronchitis | 1.3 (0.03) | 1.0 (0.03) | 1.0 (0.03) | 1.0 (0.03) | 1.1 (0.03) | 1.1 (0.03) | 1.1 (0.04) | 1.0 (0.03) | 1.0 (0.03) | 1.1 (0.04) | 1.1 (0.03) | 1.0 (0.04) | 1.0 (0.03) | 1.0 (0.02) | 1.0 (0.02) | 0.9 (0.02) | 0.7 (0.02) | 0.5 (0.01) | 0.5 (0.01) | 0.5 (0.01) | 0.4 (0.01) | 0.3 (0.01) | 0.2 (0.01)
COVID-19 | | | | | | | | | | | | | | | | | | | | | 0.1 (0.00) | 4.8 (0.05) | 6.9 (0.05)
Urinary tract infections
Any | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.8 (0.01) | 0.9 (0.02) | 0.9 (0.02) | 0.9 (0.01) | 1.0 (0.01) | 1.0 (0.01) | 0.8 (0.01) | 7.5 (0.04) | 7.0 (0.05) | 6.8 (0.05) | 6.4 (0.04) | 6.4 (0.04) | 6.4 (0.04)
Asymptomatic bacteriuria | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 7.0 (0.04) | 6.5 (0.04) | 6.3 (0.04) | 5.9 (0.04) | 5.9 (0.04) | 5.9 (0.04)
Cystitis | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.1 (0.00) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00)
Pyelonephritis | 0.5 (0.01) | 0.5 (0.01) | 0.5 (0.01) | 0.5 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.8 (0.01) | 0.6 (0.01) | 0.4 (0.00) | 0.4 (0.01) | 0.4 (0.01) | 0.4 (0.00) | 0.3 (0.00) | 0.3 (0.00)
Perinephric abscess | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
Skin and connective tissue infections
Any | 3.1 (0.04) | 3.1 (0.04) | 3.2 (0.04) | 3.4 (0.04) | 3.6 (0.04) | 3.8 (0.05) | 4.1 (0.05) | 4.2 (0.05) | 4.3 (0.05) | 4.5 (0.05) | 4.6 (0.04) | 4.8 (0.05) | 4.8 (0.05) | 4.8 (0.02) | 4.8 (0.02) | 4.9 (0.02) | 3.4 (0.02) | 4.2 (0.02) | 4.1 (0.02) | 4.2 (0.02) | 4.2 (0.02) | 4.0 (0.02) | 4.1 (0.02)
Oral and vaginal candidiasis | 0.7 (0.02) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.8 (0.02) | 0.8 (0.02) | 0.8 (0.02) | 0.9 (0.02) | 1.0 (0.02) | 1.0 (0.02) | 1.1 (0.02) | 1.1 (0.02) | 1.0 (0.01) | 1.0 (0.01) | 1.0 (0.01) | 0.7 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.5 (0.01) | 0.5 (0.01)
Onychomycosis | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00)
Intertrigo and erythematous conditions | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00)
Cellulitis and impetigo | 1.8 (0.03) | 1.9 (0.03) | 2.0 (0.03) | 2.1 (0.03) | 2.3 (0.03) | 2.4 (0.03) | 2.6 (0.03) | 2.7 (0.03) | 2.7 (0.03) | 2.8 (0.03) | 2.9 (0.03) | 3.0 (0.04) | 3.0 (0.04) | 3.0 (0.02) | 3.1 (0.02) | 3.1 (0.02) | 2.2 (0.01) | 2.9 (0.02) | 2.9 (0.02) | 3.0 (0.02) | 2.9 (0.02) | 2.8 (0.02) | 2.8 (0.02)
Foot ulcers | 0.4 (0.01) | 0.4 (0.01) | 0.5 (0.01) | 0.5 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.5 (0.00) | 0.7 (0.01) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01) | 0.7 (0.01)
Osteomyelitis | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.01) | 0.2 (0.01) | 0.2 (0.00) | 0.2 (0.01) | 0.2 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.00) | 0.3 (0.00) | 0.3 (0.00) | 0.2 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00)
Necrotizing fasciitis | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.1 (0.00) | 0.1 (0.00)
Fournier’s gangrene | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00)
Hospital-acquired infections
Any | 2.6 (0.04) | 2.5 (0.04) | 2.6 (0.04) | 2.7 (0.04) | 2.8 (0.04) | 3.0 (0.04) | 3.2 (0.05) | 3.3 (0.06) | 3.6 (0.06) | 3.9 (0.07) | 4.0 (0.06) | 4.3 (0.07) | 4.6 (0.08) | 4.8 (0.04) | 5.3 (0.04) | 6.0 (0.05) | 4.5 (0.03) | 5.4 (0.04) | 5.8 (0.05) | 6.0 (0.05) | 6.1 (0.05) | 6.3 (0.05) | 6.2 (0.05)
Sepsis | 2.1 (0.04) | 2.0 (0.04) | 2.0 (0.04) | 2.1 (0.04) | 2.3 (0.04) | 2.4 (0.05) | 2.6 (0.05) | 2.8 (0.06) | 3.0 (0.06) | 3.3 (0.07) | 3.4 (0.06) | 3.7 (0.07) | 4.0 (0.08) | 4.3 (0.04) | 4.8 (0.04) | 5.6 (0.05) | 4.2 (0.03) | 5.0 (0.04) | 5.3 (0.05) | 5.6 (0.05) | 5.6 (0.05) | 5.8 (0.05) | 5.7 (0.05)
Postoperative wound infections | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.7 (0.01) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.7 (0.02) | 0.6 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.4 (0.00) | 0.5 (0.01) | 0.5 (0.01) | 0.6 (0.01) | 0.6 (0.01) | 0.5 (0.01) | 0.6 (0.01)
Other infections associated with diabetes
Any | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00)
Necrotizing otitis externa | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
Mucormycosis | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
Emphysematous cholecystitis | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.1 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00) | 0.2 (0.00)
Other
Tuberculosis | 0.1 (0.01) | 0.1 (0.00) | 0.1 (0.00) | 0.1 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0 (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00) | 0.0^1^ (0.00)
HIV | 0.5 (0.05) | 0.5 (0.04) | 0.4 (0.04) | 0.4 (0.04) | 0.4 (0.03) | 0.5 (0.04) | 0.4 (0.04) | 0.5 (0.04) | 0.4 (0.03) | 0.4 (0.03) | 0.4 (0.04) | 0.4 (0.04) | 0.4 (0.03) | 0.4 (0.01) | 0.4 (0.01) | 0.3 (0.01) | 0.2 (0.01) | 0.4 (0.01) | 0.4 (0.01) | 0.4 (0.01) | 0.3 (0.01) | 0.3 (0.01) | 0.3 (0.01)

Diabetes status and infections are defined based on International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age standardized to the HCUP 2020 National (Nationwide) Inpatient Sample (NIS), using age groups 0–44, 45–64, and ≥65 years. COVID-19, coronavirus disease of 2019; HIV, human immunodeficiency virus.

^1^ Estimates are 0.0 (0.00) due to rounding; estimates are <0.05 (<0.005).

SOURCE: Healthcare Cost and Utilization Project (HCUP) 1999–2021

APPENDIX TABLE A4.

Age-Standardized Percentage of Outpatient Visits Listing Any Infection, by Diabetes Status, U.S., 1999–2022

SURVEY YEAR | DIABETES | | NO DIABETES
SURVEY YEAR | Weighted N | Percent (SE) | Weighted N | Percent (SE)
Physician Office Visits
1999 | 34,067,308 | 3.4 (0.72) | 715,567,725 | 3.4 (0.35)
2000 | 39,447,762 | 2.7 (0.56) | 771,777,390 | 3.0 (0.29)
2001 | 42,808,759 | 2.9 (1.08)^1^ | 836,435,493 | 2.6 (0.25)
2002 | 44,619,757 | 2.7 (1.03)^1^ | 843,325,957 | 2.9 (0.22)
2003 | 43,602,562 | 5.1 (1.49) | 858,213,021 | 3.0 (0.34)
2004 | 45,595,628 | 5.0 (1.59)^1^ | 862,995,686 | 3.0 (0.24)
2005 | 44,720,898 | 5.1 (2.10)^2^ | 906,914,441 | 3.1 (0.22)
2006 | 40,056,600 | 3.9 (1.51)^1^ | 847,575,590 | 3.0 (0.22)
2007 | 44,497,490 | 3.1 (0.99)^1^ | 922,326,411 | 2.6 (0.19)
2008 | 46,389,417 | 2.8 (1.12)^2^ | 887,505,634 | 3.3 (0.29)
2009 | 57,316,121 | 1.5 (0.55)^1^ | 949,356,661 | 3.4 (0.25)
2010 | 49,947,980 | 2.6 (0.55) | 938,409,852 | 3.5 (0.28)
2011 | 51,906,661 | 1.0 (0.33)^1^ | 909,608,811 | 3.4 (0.26)
2012 | 43,731,741 | 3.5 (0.86) | 884,898,212 | 3.5 (0.15)
2013 | 51,122,745 | 2.1 (0.56) | 871,473,700 | 3.7 (0.20)
2014 | 55,471,018 | 2.6 (0.70) | 829,236,152 | 3.4 (0.20)
2015 | 69,316,388 | ^3^ | 921,492,098 | 3.1 (0.35)
2016 | 44,489,658 | 1.9 (0.63)^1^ | 839,235,468 | 2.9 (0.26)
2018 | 52,522,624 | 1.5 (0.65)^2^ | 807,863,015 | 2.5 (0.40)
2019 | 66,337,756 | 1.5 (0.64)^2^ | 970,146,600 | 2.5 (0.35)
Community Health Center Visits
1999 | 334,973 | 25.2 (12.56)^2^ | 6,763,848 | 3.2 (1.02)^1^
2000 | 440,694 | ^3^ | 11,876,153 | 4.0 (1.45)^1^
2001 | 59,553 | ^3^ | 1,182,864 | ^3^
2002 | 224,040 | ^3^ | 1,810,737 | ^3^
2003 | 178,732 | ^3^ | 4,028,441 | 2.3 (1.08)^2^
2004 | 323,285 | ^3^ | 1,942,561 | 8.0 (3.32)^2^
2005 | 580,102 | ^3^ | 11,401,958 | ^3^
2006 | 1,243,257 | 3.8 (1.84)^2^ | 13,078,778 | 5.2 (1.54)
2007 | 2,153,264 | 6.9 (2.96)^2^ | 25,344,085 | 2.9 (0.65)
2008 | 1,905,758 | 2.4 (0.99)^2^ | 20,168,009 | 3.3 (0.79)
2009 | 3,774,130 | ^3^ | 27,349,574 | 4.8 (1.03)
2010 | 2,061,392 | ^3^ | 18,382,781 | 3.9 (0.50)
2011 | 2,644,960 | 3.1 (1.16)^1^ | 22,868,400 | 6.6 (1.35)
2012 | 5,993,737 | 4.5 (0.87) | 59,338,985 | 5.7 (0.51)
2013 | 4,769,547 | 3.3 (0.63) | 48,834,889 | 5.6 (0.50)
2014 | 6,294,585 | 3.7 (0.68) | 52,233,411 | 4.9 (0.31)
2015 | 5,681,351 | 4.1 (1.03) | 45,629,073 | 5.1 (0.32)
2022 | 31,740,670 | 4.2 (0.57) | 337,399,934 | 3.1 (0.28)

Diabetes status and infections are defined based on International Classification of Diseases, Ninth and Tenth Revision codes (Appendix Table A1). Data are age-standardized to the NAMCS 1999–2016, 2018–2019, 2022, using age groups 0–44, 45–64, and ≥65 years. SE, standard error.

^1^ Relative standard error >30%–40%

^2^ Relative standard error >40%–50%

^3^ Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Ambulatory Medical Care Surveys (NAMCS) 1999–2022