# Diabetes in Children and Adolescents

## Summary

Diabetes is one of the most common chronic diseases among children and adolescents under age 20 years in the United States. Classifying diabetes in youth as either type 1 or type 2 is challenging, especially as obesity—once associated primarily with type 2 diabetes—is now common in youth with type 1 diabetes. Between 2001 and 2017, the estimated prevalence of type 1 diabetes in U.S. youth increased by 45%, with the largest increases among non-Hispanic White and non-Hispanic Black youth. During the same period, the prevalence of type 2 diabetes increased by 95%, with the largest increases among non-Hispanic Black and Hispanic youth.

Risk factors for type 1 diabetes include genetics, particularly the human leukocyte antigen (HLA) region, as well as environmental factors such as viruses and early-life diet and growth. Type 2 risk factors include genetics, intrauterine exposure to maternal obesity and diabetes, high gestational weight gain, and postnatal obesity.

Youth with type 2 diabetes often experience complications that are more severe compared to those with type 1 diabetes at the same age and disease duration, as well as compared to people with adult-onset type 2 diabetes. Cardiovascular disease risk factors, such as high blood pressure and abnormal lipids, appear shortly after type 2 diabetes diagnosis, especially in youth of non-White racial and ethnic backgrounds. As more youth develop diabetes, especially in disadvantaged populations, addressing disparities in care and preventing complications are critical to reducing both health and economic burdens.

## Introduction

The prevalence and incidence of diabetes in youth continue to increase in the United States. Projections suggest that the number of youth age <20 years with type 1 and type 2 diabetes may increase by 23% and 50% by 2050, respectively, with the steepest increases among non-White youth and females (1). Furthermore, diabetes is a leading cause of eye disease, kidney disease, neuropathy, and coronary and peripheral vascular disease later in life. Youth from non-White and low-income backgrounds are at higher risk for developing complications and experiencing worse outcomes. Major risk factors associated with most diabetes-related complications in youth include duration of diabetes and glycemic management (glycated hemoglobin [A1C] levels). Cardiovascular disease (CVD) risk factors (e.g., elevated blood pressure, dyslipidemia, and obesity) may also appear after short durations, especially in youth with type 2 diabetes and youth of non-White background. Puberty brings hormonal changes that worsen insulin resistance and may accelerate complications, particularly in youth with type 2 diabetes. Importantly, recent data suggest higher mortality rates in youth diagnosed with type 2 versus type 1 diabetes before age 20 years.

This article provides a comprehensive review of diabetes and its complications among children and adolescents under age 20 years in North America, updating the Diabetes in America, 3rd edition, chapter Diabetes in Youth (2). Details on treatment and self-care practices in youth and adults with type 1 and type 2 diabetes are described in the Diabetes in America article Medication Use and Self-Care Practices in Persons With Diabetes (3).

## Definitions and Classifications of Diabetes in Youth

Diabetes is broadly classified into type 1 diabetes, type 2 diabetes, gestational diabetes, and other forms of diabetes (monogenic and secondary). This article focuses on the two most common forms of pediatric diabetes: type 1 and type 2 diabetes. Monogenic forms of diabetes that affect children, such as maturity-onset diabetes of the young (MODY) and neonatal diabetes, are described in detail in the Diabetes in America article Monogenic Forms of Diabetes (4).

### Type 1 Diabetes in Youth

Type 1 diabetes is caused by immune-mediated β-cell destruction leading to insulin deficiency. Symptoms are usually rapid in onset and include polyuria, polydipsia, weight loss, nausea, abdominal pain, vomiting, headaches, altered mental status, and ketoacidosis. Insulin therapy is necessary for survival (5).

The autoimmune destruction of the β-cells is mediated by T cells and accompanied by the formation of autoantibodies, such as those against the 65 kD isoform of glutamic acid decarboxylase (GADA), those against the zinc transporter 8 (ZnT8A), insulinoma-associated-2 antibodies (IA-2A), insulin autoantibodies (IAA), and islet cell autoantibodies (ICA). These antibodies are present before the appearance of clinical disease and predict disease development (6,7,8). The presence of each antibody at diagnosis varies with age of onset, sex, and race/ethnicity (9,10,11), but one or more autoantibodies are present at diagnosis of type 1 diabetes in 80%–90% of affected children (5). If antibodies are present in the context of clear insulinopenia and ketosis, a diagnosis of autoimmune type 1 diabetes or type 1a diabetes is given. If patients have a clinical picture consistent with type 1 diabetes, but no antibodies are present, the American Diabetes Association (ADA) recognizes a category labeled type 1b diabetes (or idiopathic type 1 diabetes). Patients with type 1b diabetes tend to be older, are often of African or Asian descent, and have a greater body mass index (BMI, kg/m^2^) than age-matched children with autoimmune type 1 diabetes (5). It is not clear whether these patients have a different underlying pathology (such as a MODY) or if they manifest autoantibodies that are not measured by common assays.

Four distinct stages in the natural history of type 1 diabetes have been described and recommended by the International Society for Pediatric and Adolescent Diabetes (ISPAD) (5,12,13). Stage 1 is defined by the presence of two or more islet autoantibodies with normoglycemia and is presymptomatic. Stage 2 is also defined by the presence of two or more autoantibodies but includes progression to glucose intolerance, or dysglycemia (i.e., oral glucose tolerance test [OGTT], A1C), and is likewise presymptomatic. Stage 3 is defined by the onset of clinical symptoms and signs of diabetes and measures of glycemia meeting ADA criteria for the diagnosis of diabetes (5,12). Lastly, Stage 4 includes long-standing type 1 diabetes (13). At Stage 1, the 5-year risk of developing symptomatic type 1 diabetes is 44%, while at Stage 2, the 5-year risk is 75% (12,14,15).

### Type 2 Diabetes in Youth

The pathophysiology of youth-onset type 2 diabetes is less understood than that of type 1 diabetes. Once thought to be a disease of adulthood, type 2 diabetes is increasingly recognized in children and adolescents, reportedly accounting for 20%–50% of new-onset diabetes in pediatric populations (age <20 years) within the United States (16,17,18) and disproportionately affecting youth of non-White race, especially non-Hispanic Black, Hispanic, South and East Asian, Pacific Island Native, and American Indian/First Nation peoples (19,20,21,22,23,24). Youth-onset type 2 diabetes usually presents in mid- to late-puberty, a period of physiologic insulin resistance, which is greatly exacerbated by underlying obesity (25,26). The increase in type 2 diabetes in youth is thought to be secondary to concurrent increases in the prevalence and severity of obesity. This form of diabetes is primarily characterized by insulin resistance detected at the level of skeletal muscle, liver, and adipose tissues, with a failure of β-cell compensation and relative insulin deficiency (5,27). The pace with which children progress through stages of obesity, insulin resistance, and glucose intolerance to type 2 diabetes is not fully understood. However, data from the Restoring Insulin Secretion (RISE) study demonstrated a more rapid decline in β-cell function in youth than in adults with impaired glucose tolerance or recently diagnosed type 2 diabetes (28); this observation has been confirmed by others (29,30) and may involve a unique, yet unidentified, pathophysiological component. A critical question is whether the decline is reversible or preventable, if caught in the earliest stages.

Pediatric patients with type 2 diabetes usually have overweight or obesity (BMI ≥85th percentile for age and sex), and comorbidities, such as hypertension and dyslipidemia, can be present at diagnosis. Often, there is a strong family history of diabetes in first- and second-degree family members. Weight loss at diagnosis is less common than in type 1 diabetes patients, and acanthosis nigricans, a sign of insulin resistance, is frequently identified on examination. Patients usually present with evidence of residual β-cell function, although no standardized cutoffs exist for insulin or C-peptide levels. These patients typically lack evidence of autoimmunity. Ketosis is less common than in type 1 diabetes, as individuals with type 2 diabetes usually produce enough insulin to prevent lipolysis and ketogenesis. Insulin may or may not be required at diagnosis or for long-term treatment of hyperglycemia, but insulin therapy is not required for survival (5). Of note, youth-onset type 2 diabetes can sometimes be difficult to diagnose because of limited symptoms; however, the prevalence of undiagnosed prediabetes and type 2 diabetes is lower in adolescents compared to adults (31,32). Still, during this time of undiagnosed diabetes, exposure to even mild hyperglycemia may increase the risk of future microvascular and macrovascular complications (5).

### Limitations and Challenges of Traditional Classification Approaches

Because of clinical differences at the time of diagnosis, a presumptive clinical classification of patients as having type 1 diabetes or type 2 diabetes is possible, although not always clear-cut. The weight distribution of children with type 1 diabetes is usually proportionate to the weight distribution in the general population (33,34). Thus, approximately 20%–40% of children with type 1 diabetes are now overweight (depending on race/ethnicity), although the degree of excess adiposity (or weight) is typically less than in youth with type 2 diabetes (33,35,36,37). The presence of acanthosis nigricans, hypertension, or hyperlipidemia at diabetes onset is more consistent with insulin resistance and type 2 diabetes. However, with hyperglycemia and insulinopenia, there is some degree of insulin resistance in patients with type 1 diabetes as well. Patients with type 1 diabetes are three times more likely to report a family history of type 2 diabetes than the general population (38). Although ketoacidosis is more common with type 1 diabetes, with approximately 25%–30% of youth with type 1 diabetes presenting with ketoacidosis at diagnosis (39,40), up to 29% of patients with type 2 diabetes may also have ketosis at presentation because of hyperglycemia-induced β-cell toxicity, resulting in very low endogenous insulin/C-peptide levels (41). Therefore, C-peptide levels may be low at the diagnosis of type 2 diabetes and may be normal during the honeymoon phase of type 1 diabetes and thus are not always helpful for the classification of the type of diabetes at the onset of diabetes (42).

Adolescents with obesity with a clinical picture suggestive of type 2 diabetes can present with ketoacidosis of varying degrees (41,43) or have evidence of autoimmunity (44). In such situations, due to the absence of standard case definitions, terms such as “type 1.5 diabetes,” “double,” “hybrid,” or “mixed” diabetes have been used (45). Although not part of the ADA classification system, these terms are familiar to most endocrinologists and found in well-respected journals. The current ADA etiologic classification of diabetes poses important practical challenges for researchers and clinicians because it does not provide operational definitions for the markers used to define pathophysiologic drivers of diabetes (i.e., polygenic risk score, autoimmunity, insulin resistance, insulin deficiency) (5). Thus, no standard case definitions exist for epidemiologic research or surveillance of pediatric diabetes. In addition, the ADA framework assumes that there are two distinct types of diabetes, with little or no overlap (5).

### Approaches to Classification of Diabetes in Youth

The SEARCH for Diabetes in Youth study (SEARCH) developed a classification approach based on the 1997 ADA framework (46), using two key markers, autoimmunity and insulin sensitivity. Autoimmunity was based on positive titers for GADA or IA-2A (≥5 NIDDK U/mL), while insulin sensitivity (IS) was estimated using an equation validated by a euglycemic-hyperinsulinemic clamp study in participants with and without diabetes (47): IS = exp [4.64725 - 0.02032*(waist, cm) - 0.09779*(A1C, %) - 0.00235*(triglyceride, mg/dL)]. The study established the range of IS for youth without diabetes by applying the equation to 2,860 multiracial youth age 12–20 years participating in the U.S. National Health and Nutrition Examination Surveys (NHANES) in 1999–2004, and insulin resistance was defined as an IS value below the 25th percentile (IS <8.15) for NHANES youth.

Based on these cut points, 2,291 youth who were diagnosed with diabetes in 2002–2006 were classified into four mutually exclusive groups: autoimmune and insulin sensitive, autoimmune and insulin resistant, non-autoimmune and insulin sensitive, and non-autoimmune and insulin resistant. Most youth fell into traditional categories associated with type 1 diabetes (autoimmune and insulin-sensitive diabetes; 54.5%) and type 2 diabetes (non-autoimmune and insulin-resistant diabetes; 15.9%). Another group had both autoantibodies and obesity (autoimmune and insulin resistant) and was likely to represent individuals with autoimmune type 1 diabetes and obesity, a phenotype that has grown as a result of the increase in the prevalence of obesity but is unlikely to be a distinct etiologic entity. This group shared similar human leukocyte antigen (HLA) genotypes, autoantibody profiles, and β-cell decline rates with the autoimmune and insulin-sensitive group, supporting the conclusion that these individuals had type 1 diabetes with concurrent obesity, not a distinct subtype. The fourth group had no autoimmunity or insulin resistance (approximately 10% of all participants), suggesting potential monogenic diabetes or the need for further testing. More recent efforts have demonstrated that genetic risk scores can effectively aid in the classification of diabetes type across self-reported race/ethnicity groups (48).

These findings suggest that standard case definitions can be used to classify the type of diabetes in youth (Figure 1) (49): type 1 diabetes should be defined by autoimmunity, regardless of insulin resistance or obesity, while type 2 diabetes requires the absence of diabetes-related autoantibodies and evidence of insulin resistance or obesity. Additional genetic or antibody testing may be needed for some unclassifiable cases. This classification system is not yet standard practice and has not been evaluated in other populations. However, SEARCH found that provider-assigned diagnoses generally agreed well with these etiological classifications, at least for individuals who fit the typical pictures of type 1 and type 2 diabetes (46,50). For public health surveillance of pediatric diabetes, using provider-assigned types with periodic validation via antibody testing and waist circumference may be a cost-effective approach (46).

## Burden of Diabetes Among Children and Adolescents

Nationwide or nationally representative prospective registries provide the most accurate estimates of diabetes incidence and prevalence among children and adolescents, particularly when ascertainment strategies are consistent over time and capture a high proportion of the underlying population (51). Much of the knowledge of the burden of childhood type 1 diabetes has been generated by large collaborative efforts based on standardized registry data, such as the worldwide SWEET Registry (52), the EURODIAB study in Europe (53), and the SEARCH study in the United States (54). These registries showed that, while at the start of the 20th century, type 1 diabetes was rare and rapidly fatal, by the end of the century, a steady increase in incidence had been reported in many parts of the world (53,54). Nevertheless, epidemiologic data for temporal trends in youth-onset diabetes, by type, are limited for most of the global population of children and adolescents, including North America.

In the first two decades of the 21st century, SEARCH, funded by the Centers for Disease Control and Prevention (CDC) and the National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK), estimated the prevalence and incidence of diabetes among U.S. youth age <20 years according to type of diabetes, age, sex, and race/ethnicity and characterized selected acute and chronic complications of diabetes and their risk factors. SEARCH prevalence data were collected from clinical centers located in California (Kaiser Permanente Southern California members in 7 counties, including Los Angeles), Colorado (residents of 14 counties, including Denver), Ohio (residents of 8 counties, including Cincinnati), South Carolina (residents of 4 counties, including Columbia), Washington State (residents of 5 counties, including Seattle), as well as Indian Health Services users in select areas of Arizona and New Mexico (54). For incidence data, the entire states of South Carolina and Colorado were included along with the other areas noted.

The SEARCH surveillance work informed a subsequent initiative for surveillance of diabetes by type in youth (age <18 years) and young adults (age 18–44 years) based on information in electronic health records (Diabetes in Children and Young Adults [DiCAYA]) (55). This surveillance effort was conducted at several U.S. sites from 2020 to 2025; no incidence rates or prevalence estimates have been reported to date. The Comprehensive Analysis, Surveillance, and Statistics Initiative for Diabetes in the Young (CASSIDY) study initiated in fall 2025 will conduct diabetes surveillance across five clinical centers to estimate incidence and prevalence of diabetes in youth and young adults in the United States (56).

In addition to SEARCH, the Philadelphia Pediatric Diabetes Registry published type 1 diabetes incidence data for 2000 through 2004 for three race/ethnicity groups. Other data sets have been used to estimate the burden of pediatric type 1 diabetes in the United States and Canada. These data sources include the NHANES, the National Health Interview Survey (NHIS), and static analyses of MarketScan Medicaid data, MarketScan Commercial insurance claims, and claims from a universal health insurance program in British Columbia, Canada. Surveillance data of youth-onset type 2 diabetes in North America are limited to SEARCH, the NHANES, and a static analysis of MarketScan Medicaid data. Prevalence estimates are presented per 1,000, and incidence estimates are presented per 100,000.

### Type 1 Diabetes

The majority of worldwide epidemiologic data on youth-onset type 1 diabetes are based on a clinical definition, including physician diagnosis and daily insulin injections (57). In addition, most European studies have limited the age range of populations to <15 years to avoid misclassification of the type of diabetes. Except for SEARCH and the Philadelphia Registry (58), studies have assumed, but not confirmed using measured diabetes autoantibodies, that “type 1” diabetes is autoimmune-mediated diabetes. Selected data on prevalence, incidence, trends, and projections for the prevalence and incidence of type 1 diabetes in youth age <20 years from North American studies are summarized in this section, with a focus on age, sex, and race/ethnicity-specific estimates.

#### Prevalence and Trends in the Prevalence of Type 1 Diabetes

Prevalence data may not fully capture the impact of diabetes, since prevalence is determined not only by disease incidence but also by survival, which may vary across populations. Prevalence data, however, are useful in determining the public health impact of type 1 diabetes. Selected estimates of type 1 diabetes prevalence in different North American populations by age group, sex, and race/ethnicity are shown in Figure 2 (59,60,61,62,63,64). Prevalence estimates in 2017 for type 1 diabetes by age group, sex, and race/ethnicity categories were provided by the population-based SEARCH study. Nuanced race/ethnicity, age group, and sex specific estimates are not available from the NHANES (59) and NHIS (60) due to unstable estimates in small strata from the complex sampling and weighting design nor from a claims-based study from British Columbia (61). Comparisons across surveillance systems should consider that diabetes type is estimated in the NHANES and NHIS via parental proxy and medication, and thus, misclassification of diabetes type is potentially an important issue. Further, the population under surveillance (denominator) varies across different studies. For example, the population under surveillance is the census of the age and geographically eligible population in SEARCH, NHANES, NHIS, while it is healthcare utilizers for claims-based registries, which may be limited to the population covered (e.g., commercially insured vs. Medicaid).

SEARCH, the only U.S. population-based study of youth-onset diabetes, identified 7,759 youth with type 1 diabetes in 2017 among approximately 3.61 million ethnically diverse youth age <20 years under surveillance (62). The prevalence of type 1 diabetes (per 1,000 youth age <20 years) was 2.15 overall (95% confidence interval [CI] 2.10–2.20) and varied with age and race/ethnicity for females and males. Overall, by race/ethnicity, prevalence (per 1,000 youth age <20 years) was highest among non-Hispanic White youth (2.79), followed by non-Hispanic Black (2.18) and Hispanic (1.56) youth, and lowest among Asian and Pacific Islander and American Indian youth (0.76 and 0.56, respectively). Among females, the lowest prevalence was among American Indian youth (ranging from 0.15 at age 0–4 years to 1.29 at age 15–19 years), followed by Asian and Pacific Islander (0.15 and 1.56, respectively), Hispanic (0.11 and 2.79, respectively), and non-Hispanic Black (0.39 and 4.15, respectively) youth, and highest among non-Hispanic White youth (0.38 and 4.77, respectively). Among males, the lowest prevalence was among American Indian youth (ranging from 0.11 at age 0–4 years to 0.81 at age 15–19 years), followed by Asian and Pacific Islander (0.12 and 1.03, respectively), Hispanic (0.16 and 2.74, respectively), and non-Hispanic Black (0.32 and 4.00, respectively) youth, and highest among non-Hispanic White youth (0.34 and 5.49, respectively).

Using data from the NHANES 1999–2010, Menke et al. estimated the prevalence of type 1 diabetes among youth of current age 1–19 years to be 2.4 per 1,000 (95% CI 1.7–3.3) (using either definition 1: insulin within 1 year of diagnosis and current use of insulin and diagnosed age <30 years, or definition 2: definition 1, but age <40 years at diagnosis) (65). A limitation of this definition is that many youth with type 2 diabetes use insulin (66), thus potentially misclassifying diabetes type. A follow-up study of the same NHANES data by Demmer et al. altered the definition to classify all youth using oral blood glucose-lowering medication, with or without insulin, as type 2 (59). Based on this definition, the overall prevalence of type 1 diabetes among youth age 12–19 years was 3.8 per 1,000. In the NHANES estimates, the highest prevalence was in non-Hispanic White youth (4.3 per 1,000), followed by non-Hispanic Black youth (2.8 per 1,000), and lowest in Mexican American youth (1.4 per 1,000). In the NHIS 2019–2022, the prevalence of type 1 diabetes in youth age <18 years was estimated at 3.5 per 1,000 (95% CI 2.8–4.4) based on parental proxy and current insulin use (60). The highest prevalence was in non-Hispanic White youth (3.9 per 1,000), followed by Hispanic youth (3.5 per 1,000), and lowest in non-Hispanic Black youth (2.6 per 1,000). The prevalence of type 1 diabetes using the definitions in the NHANES and NHIS is likely overestimated due to reliance on parental report (67). The NHANES estimates offer important nuance regarding youth with Hispanic ethnicity by oversampling Mexican Americans and providing separate estimates for youth of Mexican American ethnicity compared to other Hispanic ethnicities (not including Mexican American). The prevalence estimates for Mexican American youth in this survey are much lower compared to youth of Hispanic (non-Mexican American) ethnicity, reflecting the diversity of Hispanic ethnicity as a category.

A study of pediatric diabetes in the MarketScan Multistate Medicaid Database estimated the prevalence of type 1 diabetes in 2016 in youth age <18 years to be 2.34 per 1,000 pediatric patients who were in the database, with similar age and race/ethnicity patterns as observed in SEARCH (63). A study using the MarketScan Multistate Commercial Database found a remarkably similar prevalence estimate in 2013 of 2.32 per 1,000 pediatric patients (age <18 years) in care (64). A comparable type 1 diabetes prevalence was seen in a study of administrative healthcare and prescription data from British Columbia, in youth age <20 years (1.76 per 1,000 in 2002–2003 and 2.34 per 1,000 in 2012–2013, with an overall annualized percent change of 2.84% over 11 years) (61). It should be noted that the denominator used by the MarketScan studies is pediatric healthcare users (Medicaid or commercial insurance, depending on the database); in contrast, the denominators for SEARCH and the Canadian registry are census-based or membership-based (for the SEARCH health plan site).

Changes in the prevalence of type 1 diabetes in the United States have been reported by SEARCH (62,68). In 2001, 4,958 of 3.3 million youth were diagnosed with type 1 diabetes, with a prevalence of 1.48 per 1,000 youth age <20 years (95% CI 1.44–1.52). In 2009, 6,672 of 3.4 million youth were diagnosed with type 1 diabetes, with a prevalence of 1.93 per 1,000 youth age <20 years (95% CI 1.88–1.97). In 2017, 7,759 of 3.6 million youth were diagnosed with a prevalence of 2.15 per 1,000 youth age <20 years (95% CI 2.10–2.20). The prevalence of type 1 diabetes increased significantly between 2001 and 2017 in all sex, age, and race/ethnicity subgroups, representing an absolute increase of 0.67 per 1,000 youth age <20 years and a 45.1% relative increase over 16 years (62). Potential reasons for the increasing prevalence of type 1 diabetes are discussed in the Risk Factors for Diabetes in Youth section.

#### Incidence and Trends in the Incidence of Type 1 Diabetes

Worldwide, the incidence of type 1 diabetes in children age <15 years varies substantially with geographic location, from <0.1 in Ethiopia, Venezuela, and Papua New Guinea up to >50 per 100,000 per year in Finland (69). In the 10th edition of the International Diabetes Federation (IDF) Atlas published in 2022, the United States ranked 12th in the world for age-standardized type 1 diabetes incidence among youth age <15 years and second only to India in the highest number of incident cases of type 1 diabetes in 2021 (69). While clear-cut differences in the occurrence of youth-onset type 1 diabetes exist across geographic boundaries, likely reflecting different pools of susceptibility genes and/or different occurrence of environmental determinants of the disease, the clinical picture and the severity of the disease remain constant (70). Thus, the observed differences in incidence throughout the world are unlikely to be confounded by misclassification of the type of diabetes. Across most geographic areas, including in the United States, incidence peaks at ages 5–9 and 10–14 years (54,57). The early peak is possibly caused by increased exposure to diabetogenic factors related to social mixing at preschool or school entry (71). The incidence peak at puberty may be related to sex hormones increasing the risk of progression from islet autoimmunity to type 1 diabetes or to alterations in lifestyle (72,73).

Much of the geographic variation in the incidence of type 1 diabetes may reflect differences in the ancestral composition of populations throughout the world. Traditionally, populations of European ancestry have a higher risk of developing type 1 diabetes compared to other racial and ethnic groups. The reasons for this remain elusive; however, different frequencies of high-risk genes are a likely contributor. Among U.S. youth in SEARCH, non-Hispanic White youth were about 1.5 times as likely to develop type 1 diabetes as Hispanic youth, 1.2 times as likely as non-Hispanic Black youth, 2.8 times as likely as Asian and Pacific Islander youth, and 3.4 times as likely as American Indian youth (54). Between 2002 and 2018, SEARCH identified 18,169 youth age <20 years with incident type 1 diabetes in 85 million person-years (54). In 2017–2018, the incidence of type 1 diabetes (per 100,00 per year in youth age <20 years) was highest among non-Hispanic White youth (26.4), followed in descending order by non-Hispanic Black (22.1), Hispanic (17.7), and Asian and Pacific Islander (9.4) youth, with the lowest rates observed in American Indian youth (7.8). The age-group stratified rates of type 1 diabetes (per 100,000 per year in youth age <20 years) by each race/ethnicity category are presented in Figure 3A (54,61,74). The incidence (per 100,000 per year) of type 1 diabetes in youth age <20 years was highest in non-Hispanic White youth (18.2 at age 0–4 years; 29.6 at age 5–9 years; 41.2 at age 10–14 years; and 16.0 at age 15–19 years), followed in descending order of incidence by non-Hispanic Black (16.4, 26.9, 31.7, and 13.0, respectively) and Hispanic (8.2, 23.3, 28.7, and 16.1, respectively) youth, with the lowest incidence observed among Asian and Pacific Islander (8.3, 10.8, 11.5, and 6.7, respectively) and American Indian (7.8 at age 0–19 years) youth. A population-based study using linked administrative databases from a universal health insurance program in British Columbia, reported very similar age-group incidence estimates as those observed in SEARCH (Figure 3A) (61).

A study of type 1 diabetes incidence using the Clinformatics Datamart Database containing over 61 million commercially insured people in the United States identified incident cases based on International Classification of Diseases, Ninth Revision (ICD-9) diagnosis codes and at least one prescription for insulin at an outpatient visit between 2001 and 2015 (74). The authors identified 13,302 youth with presumptive type 1 diabetes who met the criteria for incidence and calculated an incidence rate of 23.0 per 100,000 (95% CI 22.0–24.1) for youth age <5 years, 29.9 per 100,000 (95% CI 28.9–31.0) for youth age 5–9 years, 45.5 per 100,000 (95% CI 44.2–46.8) for youth age 10–14 years, and 36.4 per 100,000 (95% CI 35.3–37.6) for youth age 15–19 years (Figure 3A) (74). These rates were higher than those reported by SEARCH between 2002 and 2018 (14.4, 29.9, 45.5, and 36.4 per 100,000, respectively) (54). A similar consideration should be made when comparing MarketScan estimates to SEARCH estimates and the Canadian publications because the former uses a denominator of pediatric commercial insurance users, whereas SEARCH and the Canadian estimates use the census.

Most (75,76,77,78,79), but not all (80,81,82,83), population-based registries have shown an increasing incidence of youth-onset type 1 diabetes over time (84). Similarly, the EURODIAB study, a large European survey including 26 population-based registries in 17 countries, showed a 3.4% (95% CI 2.8%–3.9%) average annual percentage change for the period 1989–2013 (53). The rates of increase were similar in boys and girls in the 0–4-years age group (3.7% and 3.7% per year, respectively) and in the 5–9-years age group (3.4% and 3.7% per year, respectively) but were higher in boys than girls in the 10–14-years age group (3.3% and 2.6% per year, respectively). The overall rate of increase by period suggests a slowing in 2004–2008 but a rate of increase in 2009–2013 that matched previous levels.

Data from the United States, where registry efforts have been less coordinated than in Europe, suggest that annualized percentage increases in incidence vary by race/ethnicity subgroups (Figure 4A) (54,61,74). SEARCH reported a significant upward trend in age-, sex-, and race/ethnicity-adjusted incidence of type 1 diabetes in youth age <20 years from 19.5 cases per 100,000 per year in 2002–2003 to 22.2 cases per 100,000 per year in 2017–2018 with an adjusted (for age, sex, and race or ethnicity group) annualized percent change (AAPC) of 2.02% (54). These trends reported by SEARCH are similar to those seen in Europe (53) but slightly higher than those reported in British Columbia (1.26% between 2002–2003 and 2012–2013) (61). However, surprisingly, annual rates of increase in SEARCH were highest for Asian and Pacific Islander (4.84%), Hispanic (4.14%), and non-Hispanic Black (2.93%) youth. The reasons for these steep increases in youth other than non-Hispanic White youth are not well understood and need further exploration, particularly since type 1 diabetes has traditionally been considered a condition affecting mostly populations of European ancestry.

In the Clinformatics Datamart Database of youth who utilized commercial insurance in the United States, the absolute incidence of type 1 diabetes in youth age <20 years increased by 1.9% annually between 2001 and 2015 but varied by U.S. region, with the greatest increase observed in the East South Central region (3.8%), followed by the Mountain (3.1%), East North Central (2.7%), South Atlantic (2.4%), and West North Central (2.4%) regions (74). No significant trends in incidence were observed for the West South Central, Pacific, New England, and Middle Atlantic regions. Incidence from the claims-based surveillance estimates is vulnerable to misclassification of diabetes status, type, and incidence status, which relies upon type 1 diabetes-specific ICD-Clinical Modification (CM) diagnosis coding and dispensed prescriptions for insulin. The regional variations in claims-based estimates evident in Figure 4A may reflect local health system variability in coding behavior and not true changes in the incidence of disease. Further, the denominator for the MarketScan estimates is utilization-based compared to census denominators in SEARCH estimates and the Canadian publications; this leads to higher estimates because the denominator is limited to youth who utilize healthcare.

Limited U.S. studies suggest an increase in the incidence of pediatric type 1 diabetes following the COVID-19 (coronavirus disease of 2019) pandemic; unfortunately, none are population-based. In a large cohort of youth age <20 years from the Kaiser Permanente Southern California Health Plan, the incidence of type 1 diabetes increased from 19.55 per 100,000 in 2016 to 24.3 per 100,000 in 2021 (85). Comparing 2020–2021 with 2016–2019, the incidence of type 1 diabetes was 17% higher overall (incidence rate ratio [IRR] 1.17, 95% CI 1.04–1.31) and higher among those age 10–19 years (IRR 1.17, 95% CI 1.01–1.36), males (IRR 1.18, 95% CI 1.00–1.39), and Hispanic individuals (IRR 1.21, 95% CI 1.01–1.44). In a tertiary care center in San Diego, California, new-onset type 1 diabetes care increased by 57% between March 2020 and March 2021 (86). At Duke University Hospital and Duke Pediatric Endocrinology and Diabetes Clinics, new-onset pediatric type 1 diabetes increased by 48% in 2021–2022 compared to 2018–2020, with higher BMI at onset and a larger percentage presenting in diabetic ketoacidosis (DKA) (87). In the OneFlorida+ network of the national Patient-Centered Clinical Research Network between January 2017 and June 2021, the observed incidence of type 1 diabetes in youth was higher than the model-predicted rates after March 2020 (p=0.0014) (88). The reasons for these apparent increases in incidence and severity at presentation of youth-onset type 1 diabetes, if true, are still unclear.

#### Projections

In the United States, projections suggest that if the incidence of type 1 diabetes remains stable, the number of youth with type 1 diabetes age <20 years will increase by 23% by 2050 due to population growth (1). However, if incidence continues to increase at the levels described above, the number of youth with type 1 diabetes will increase more than threefold in the United States, especially among youth other than non-Hispanic White youth (1). The Type 1 Diabetes Index project modeled the projected incidence, prevalence, and associated mortality of type 1 diabetes using the most recent incidence data for individuals age <20 years held in the IDF Atlas in 2021 (69). Between 2020 and 2040, the prevalence of type 1 diabetes is projected to increase by 46% in North America from 16.5 to 24.2 per 100,000, even if incidence, mortality, and diagnosis rates are held constant (84).

### Type 2 Diabetes

Type 2 diabetes has been traditionally viewed as an adult disease, with risk increasing with advancing age and degree and duration of obesity. However, an increasing proportion of youth with apparent type 2 diabetes has been reported since the late 1990s, especially in racially and ethnically diverse populations (89,90). The epidemiology of type 2 diabetes in youth is still unclear due to its relative rarity, the lack of uniform clinical and epidemiologic definitions, and the small number of appropriate, population-based studies. A review of the epidemiology, pathophysiology, pediatric-specific treatment response data, morbidity, and mortality of youth-onset type 2 diabetes from four U.S. studies was published in Diabetes Care in recognition of NIDDK’s 75th anniversary in 2025 (91).

Selected data on prevalence, incidence, trends, and projections for the prevalence and incidence of type 2 diabetes in youth age <20 years from North American studies are summarized in this section, with a focus on race/ethnicity-specific estimates.

#### Prevalence and Trends in the Prevalence of Type 2 Diabetes

Population-based studies, where all individuals within a geographic area undergo diabetes screening, are ideal for determining prevalence, as they capture diagnosed and undiagnosed cases. However, among the limited number of population-based studies of type 2 diabetes in youth, few conduct screening tests for type 2 diabetes, and many lack key data essential to differentiate type 2 from type 1 diabetes.

Figure 5 provides estimates of type 2 diabetes prevalence among U.S. youth age 0–19 years, by age group, sex, and race/ethnicity when available (59,62,63). Refined subgroup estimates in the past 20 years are only available from SEARCH, which identified 1,230 youth age <20 years with provider-diagnosed type 2 diabetes in 2017, in a population of 3.4 million youth (62). Prevalence was not reported for children age 0–9 years because of the small sample (n=8 in 2017). Prevalence (per 1,000) was 0.29 in youth age 10–14 years and 1.04 in youth age 15–19 years. The highest prevalence of type 2 diabetes (per 1,000) was observed among non-Hispanic Black youth (1.80), followed by American Indian (1.63), Hispanic (1.03), and Asian and Pacific Islander (0.59) youth, while the lowest prevalence was seen in non-Hispanic White youth (0.20) (62). In the MarketScan Medicaid Claims Database, Chen et al. reported a prevalence of type 2 diabetes in youth age 0–17 years of 2.12 per 1,000 Medicaid subscribers in 2016 with little variation by race/ethnicity (2.36 per 1,000 in non-Hispanic Black youth, 2.29 per 1,000 in Hispanic youth, 2.05 per 1,000 in non-Hispanic White youth, and 1.77 per 1,000 in youth of “other” race/ethnicity groups); however, misclassification or missing race/ethnicity is a known limitation of claims data (63). The higher prevalence estimates in MarketScan are likely due, in part, to using a denominator of Medicaid subscribers relative to census denominators and health plan enrollees in SEARCH. The consistency of prevalence across race/ethnicity groups in the Medicaid claims data may reflect a similar exposure to adverse social determinants of health.

In the United States, the NHANES combined six unique data sets generated in 2-year survey data collection cycles between 1999 and 2010, including 11,888 adolescents age 12–19 years who responded to a diabetes questionnaire (59). A random sample of 4,661 youth also provided fasting blood samples. Youth with type 2 diabetes were identified based on self-reports of a physician’s diagnosis and use of an oral hypoglycemic medication with or without insulin. The total prevalence of self-reported diagnosed diabetes among youth age 12–19 years in the United States was estimated to be 8.4 per 1,000. The prevalence of diagnosed type 2 diabetes was 3.6 per 1,000, with the highest estimates among non-Hispanic Black youth (4.2 per 1,000), followed by Mexican American (2.3 per 1,000) and non-Hispanic White (1.4 per 1,000) youth. In the subsample that provided a fasting blood sample, those who self-reported that they had not received a diagnosis of type 2 diabetes but had a fasting blood glucose concentration ≥126 mg/dL (≥6.99 mmol/L) were considered undiagnosed. Among the adolescents with type 2 diabetes, 34% were estimated to be undiagnosed, representing 40,611 youth (95% CI 2,850–78,373). The use of self-report has obvious limitations in the identification of the presence of diabetes, as does the poor differentiation between type 1 diabetes and type 2 diabetes.

SEARCH reported on trends in the prevalence of type 2 diabetes from 2001 to 2017 among youth age 10–19 years (62). In 2001, 588 of 1.7 million youth were diagnosed with type 2 diabetes for a prevalence of 0.34 per 1,000 (95% CI 0.31–0.37). In 2009, 819 of 1.8 million youth were diagnosed with type 2 diabetes, with a prevalence of 0.46 per 1,000 (95% CI 0.43–0.49). In 2017, 1,230 of 1.8 million youth were diagnosed with type 2 diabetes, with a prevalence of 0.67 per 1,000 (95% CI 0.63–0.70). Significant increases occurred between 2001 and 2009 in all age groups, both sexes, and in non-Hispanic White, non-Hispanic Black, and Hispanic youth, with no significant changes for Asian and Pacific Islander and American Indian youth. Between 2009 and 2017, there were significant increases for all subgroups by age, sex, and race/ethnicity, except for non-Hispanic White youth. These data demonstrate a 95.3% (95% CI 77.0%–115.4%) relative increase in type 2 diabetes prevalence over the 16 years.

A limited number of other population-based studies of childhood type 2 diabetes prevalence exist. Most were conducted in American Indian youth (21,92,93) and showed a high prevalence of type 2 diabetes. Thirty years of data collected among the Pima Indians of Arizona have shown extremely high and increasing prevalence of type 2 diabetes: from 1967–1976 to 1987–1996, the type 2 diabetes prevalence in Pima Indian youth increased from 24 to 38 per 1,000 in males and from 27 to 53 per 1,000 in females, the highest rates reported in youth to date (20); of note, this was a screened population.

#### Incidence and Trends in the Incidence of Type 2 Diabetes

The only population-based studies reporting on the incidence of type 2 diabetes in North American youth in the past 20 years in the United States and Canada are SEARCH and two studies in British Columbia and Manitoba, Canada. A summary is provided in Figure 3B (reported per 100,000 youth) (54,94,95).

In SEARCH, non-Hispanic White youth are about three times less likely to develop type 2 diabetes than Hispanic and Asian and Pacific Islander youth, about six times less likely than non-Hispanic Black youth, and almost 12 times less likely than American Indian youth (54). Confirming previous reports, SEARCH showed that type 2 diabetes accounted for a substantial proportion of all diabetes in youth other than those of non-Hispanic White race/ethnicity at age 10–19 years, especially American Indian (86.2%) and Asian and Pacific Islander (69.7%) youth, but also among non-Hispanic Black (57.8%) and Hispanic (46.1%) youth (96). Based on SEARCH data from 2018, the rates of type 2 diabetes (per 100,000 per year) were the highest among American Indian (46.0 for age 10–19 years) and non-Hispanic Black (45.2 and 39.6 for ages 10–14 and 15–19 years, respectively) youth, followed by Hispanic (18.2 and 30.0, respectively) and Asian and Pacific Islander (8.7 and 23.9, respectively) youth, and were lowest among non-Hispanic White youth (4.2 and 5.9, respectively) (54).

In a population-based study of administrative data from a university healthcare system in British Columbia, type 2 diabetes in youth was identified based on diagnosis codes and medications. Incident type 2 diabetes was identified based on the date at which they met the case-finding algorithm. In 2012–2013, the incidence of type 2 diabetes in youth age 10–19 years was 5.16 per 100,000 (94), approximately half the rate observed in SEARCH of 12.3 per 100,000 in 2012. In the population-based study in Manitoba, incident type 2 diabetes was identified using the same case-finding algorithm as in the British Columbia study. Sellers et al. reported an incidence of type 2 diabetes among children age 7–17 years in 2017–2018 of 210.78 (95% CI 177.95–249.66) per 100,000 for First Nation children and 17.31 (95% CI 13.19–22.71) per 100,000 for all other (non-First Nation) Manitoban children (95). The rate observed in the First Nation Manitoban youth is significantly higher than other populations, including American Indian youth in the SEARCH study. One influential factor may be that one-third of children with diagnosed “type 2 diabetes” in Manitoba are of Anishiniew (Oji-Cree) origin, a population that carries a specific polymorphism of the HNF-1α gene (G316S) that results in a decrease in insulin secretory capacity, predisposing them to the development of MODY (97).

These data suggest that youth-onset type 2 diabetes mainly affects non-White populations in the United States. The higher incidence among historically disadvantaged populations indicates a contribution of social and environmental factors, including a historical lack of access to culturally appropriate healthy food choices and opportunities for physical activity, as well as exposure to environmental pollutants (98). Well-designed studies of youth in Germany, Austria, France, and the United Kingdom (99,100,101) indicate that youth-onset type 2 diabetes remains a rarity, accounting for only 1%–2% of all new-onset pediatric diabetes cases. In contrast, while the SEARCH data support the notion that type 2 diabetes in youth is predominantly occurring in historically disadvantaged populations, type 2 diabetes accounted for 32.5% of all diabetes among adolescents age 10–19 years. Although differences in obesity rates and socioeconomic disparities between U.S. and European youth are likely contributors, the full explanation for these discrepancies deserves further study.

Few data exist on temporal trends in the incidence of type 2 diabetes in youth in North America over the last 20 years. Trends in the incidence of youth-onset type 2 diabetes are provided by the SEARCH study in the United States and two smaller population-based studies in British Columbia and Manitoba. SEARCH provided trends in incidence between 2002 and 2018 and the population-based cohort from British Columbia provided trends between 2002 and 2012, displayed in Figure 4B (54,94); the population-based cohort from Manitoba provided trends between 2009 and 2018 (95).

The incidence of type 2 diabetes in the SEARCH study increased at an AAPC of 5.3% between 2002–2003 and 2017–2018 (54). The annual rates of increase were highest among Asian and Pacific Islander (8.9%), Hispanic (7.2%), and non-Hispanic Black (6.0%) youth. In 2017–2018, the incidence of type 2 diabetes in youth age 15–19 years exceeded the incidence of T1D (19.7 vs. 14.6 per 100,000). In British Columbia, Amed et al. reported trends of incident type 2 diabetes in youth age 10–19 years using a population denominator between 2002 and 2012 (94). In 2002–2003, the incidence was 3.45 (95% CI 2.43–4.80) per 100,000 and increased to 5.16 (95% CI 3.86–6.78) per 100,000 in 2012–2013 with an annual percentage change in incidence of 3.74 (95% CI 1.61–5.92). The incidence increased in females from 4.43 (95% CI 2.81–6.74) to 7.21 (95% CI 5.05–10.05) and in males from 2.53 (95% CI 1.39–4.36) to 3.23 (95% CI 1.88–5.24) with the sex difference widening after 2010. In Manitoba, Sellers et al. reported trends of incident type 2 diabetes among children age 7–17 years, stratified by First Nation versus all other Manitoban children between 2009 and 2018 (95). Among First Nation children, the rate increased from 125.09 (95% CI 99.61–157.10) per 100,000 in 2009–2010 to 210.78 (95% CI 177.95–249.66) per 100,000 in 2017–2018. Among all other non-First Nation Manitoban children, incidence increased from 5.17 (95% CI 3.12–8.58) per 100,000 in 2009–2010 to 17.31 (95% CI 13.19–22.71) per 100,000 by 2017–2018. The study did not report an AAPC; significant temporal increases were detected for both First Nation and non-First Nation Manitoban youth (p<0.001). While absolute incidence rates were lower in the British Columbia registry than in SEARCH, the temporal patterns of increase were similar.

There are limited data on the incidence of youth-onset type 2 diabetes following the COVID-19 pandemic in North America. In a large cohort of youth from the Kaiser Permanente Southern California Health Plan, the incidence of type 2 diabetes increased from 14.8 per 100,000 in 2016–2019 to 24.7 per 100,000 in 2020 (85). Further, the incidence rates of type 2 diabetes in 2020–2021 compared with 2016–2019 were higher among those age 10–19 years (IRR 1.63, 95% CI 1.44–1.84), specifically among non-Hispanic Black (IRR 1.95, 95% CI 1.41–2.68) and Hispanic (IRR 1.61, 95% CI 1.39–1.86) youth. Of note, the Kaiser Permanente Southern California study is based on health plan enrollees and not the population of southern California.

#### Projections

Projections on the burden of type 2 diabetes in youth provide a disturbing picture. Models based on SEARCH data project that by 2050, even at current incidence rates, the number of youth with type 2 diabetes may increase by almost 50% (1), essentially due to the population growth of racially and ethnically diverse groups projected by the U.S. Census. However, the observed annual rate of increase of 5.3% in SEARCH between 2002 and 2018 is more than double the increase modeled by Imperatore et al. (2.3%), who estimated the prevalence of type 2 diabetes in youth would increase 178% by 2050 to 0.75 per 1,000 youth (1). If the incidence of type 2 diabetes increases, the number of youth with type 2 diabetes may increase more than fourfold (1).

## Risk Factors for Diabetes in Youth

### Type 1 Diabetes

Genetic susceptibility plays a large role in type 1 diabetes, with the HLA genotypes (DR and DQ genes) explaining approximately 40%–50% of type 1 diabetes risk (102). The genetic variation can explain part of the geographic variation in incidence, but type 1 diabetes susceptibility genes are unlikely to explain the increasing trend over time in the incidence of type 1 diabetes. Additional information can be found in the Diabetes in America article Genetics of Type 1 Diabetes (103).

Several environmental factors are involved in the disease etiology, as extensively described in the Diabetes in America article Risk Factors for Type 1 Diabetes (104). Longitudinal, collaborative efforts, such as The Environmental Determinants of Diabetes in the Young (TEDDY) study, following children at risk for type 1 diabetes from birth onwards, allow comparisons among different populations (United States, Finland, Germany, and Sweden) with different background incidence rates, different lifestyles, and environmental trends; these studies are expected to identify major environmental triggers of autoimmunity and type 1 diabetes.

#### Viruses

Viruses have long been considered a major risk factor for type 1 diabetes (105). The hypothesis is that in susceptible individuals, viral infections may trigger autoimmunity and accelerate the autoimmune destruction of β-cells, leading to type 1 diabetes (106). Many studies have focused on human enteroviruses, with some finding positive associations between enterovirus infections and the risk of type 1 diabetes or evidence that the seasonal variation seen with type 1 diabetes risk coincides with the time of enterovirus infections (105). A metagenomic virome analysis of >12,000 stool samples in TEDDY identified >600 viral taxa; however, only human enteroviruses and adenoviruses showed an association with islet autoimmunity. For enteroviruses, the species B enterovirus, including Coxsackie B viruses, was associated with an increased risk of islet autoimmunity with a preference for IAA (107); this observation was also made in the Diabetes Prediction and Prevention (DIPP) study and the Norwegian MIDIA study (Norwegian acronym for “Environmental Triggers of Type 1 Diabetes”) (108,109). Longitudinal analysis of stools from children before the onset of islet autoimmunity revealed that those who developed IAA had evidence of prolonged shedding of the same enterovirus B infection, suggesting viral persistence due to a more virulent viral strain or weaker immune response to infection. Prolonged enterovirus infection has been proposed as a mechanism that mediates β-cell damage, both by promoting β-cell dysfunction and stress and by triggering inflammation that contributes to autoimmunity (110). Adenovirus infection in the first 6 months of life has been negatively associated with islet autoimmunity, particularly the adenovirus-C species (107). The mechanism is not well understood but may involve early outcompeting Coxsackie B viruses for receptor binding. Thus, the role of viral infections in the etiology of type 1 diabetes remains controversial.

The microbial environment has changed over the last 50 years; antibiotic use has increased, while exposure to enteroviruses, helminths, and commensal bacteria has decreased (111). Consequently, the “hygiene hypothesis” proposes that the decreasing early-life exposure to infectious agents in westernized societies has led to differential maturation of the immune system, thus permitting an increased occurrence of immune-mediated disorders, such as asthma and type 1 diabetes (112); this hypothesis requires further testing.

#### Early-Life Diet

Important changes in early-life diet and feeding patterns worldwide over the last century have renewed the interest in early-life nutrition as a possible explanation for the increasing incidence of type 1 diabetes. Breastfeeding and early exposure to cow’s milk have been the most extensively studied, with conflicting findings. To adequately address the effect of infant diets on risk of type 1 diabetes, the Trial to Reduce IDDM in the Genetically at Risk (TRIGR) study, a collaborative international study group of 77 clinical centers in 15 countries, conducted a clinical trial to address the role of breastfeeding versus cow’s milk in the risk of autoimmunity and type 1 diabetes (113,114). They found that among infants at risk for type 1 diabetes, the use of highly hydrolyzed formula did not decrease the cumulative incidence of one or more diabetes-related autoantibodies up to age 10 years (115). Similarly, TEDDY found that islet autoimmunity risk was not reduced in children who received extensively hydrolyzed formula and was increased among infants who received it as their first formula (compared with non-hydrolyzed cow’s milk formula) (116).

Few studies have focused on other practices of infant feeding, such as early exposure to solid foods. Although only limited research exists, positive associations between early exposure to solid foods, such as cereals or gluten-containing foods, and the risk of type 1 diabetes have been reported (117,118). Early probiotic supplementation (in the first month of life) was shown in the TEDDY study to reduce the risk of islet autoimmunity by 60% among children with a high-risk genotype (DR3/4), suggesting a gene-environment interaction (119). The very early weeks of life may represent a window for probiotics to contribute to a favorable gut microbiota, particularly among genetically high-risk children, and prepare the developing immune system to process future acquired infections (120).

#### Early-Life Growth

A trend toward an earlier age at diagnosis of type 1 diabetes, with stable or decreasing rates later in life (121,122,123,124), has been reported, suggesting that the increasing incidence of type 1 diabetes in youth is the result of an “acceleration” of disease onset to earlier ages rather than an increased lifetime risk (125). The accelerator (126) and overload (127) hypotheses both propose that environmental risk factors prevalent in contemporary societies may accelerate the onset of type 1 diabetes (to younger ages) by increasing the demand for insulin production and thus overloading the β-cells. While the overload hypothesis has a broader perspective on the potential environmental factors in question (accelerated growth, infections, stress, and climate), the accelerator hypothesis focuses on body fatness and associated insulin resistance as the main accelerators.

The Type 1 Diabetes Intelligence study (T1DI), a large cohort of more than 10,000 prospectively followed children from the United States and Europe, found that rapid childhood growth was associated with both the onset of islet autoimmunity and progression to type 1 diabetes (128). Interestingly, they found that rapid increases in height, rather than in weight, were associated with increased risk, likely consistent with the “overload” hypothesis. The results are in agreement with those observed in TEDDY, which showed that accelerated childhood growth was associated with more rapid progression from autoimmunity to diagnosis of diabetes (129). SEARCH reported that a higher BMI was associated with a younger age at diagnosis with type 1 diabetes, but only in youth with an already substantially reduced β-cell function (130); this finding suggests that obesity may increase the risk only after initiation of autoimmunity, resulting in an accelerated β-cell decline that leads to an earlier type 1 diabetes diagnosis. Conversely, the Australian Baby Diab Study reported that weight gain early in life (birth to age 2 years) independently predicted the development of islet autoimmunity in a genetically at-risk population (131), an effect not seen in other studies (132). However, this study analyzed infant and childhood growth together, which may have obscured the different regulatory mechanisms that drive growth in infancy, childhood, and the pubertal period (133). While the main driver of growth in infancy is nutrition, growth hormone is an important factor that affects height in childhood, and sex hormones induce the pubertal growth spurt (134), emphasizing the importance of analyzing growth rates at distinct periods. These data may be interpreted to suggest that changes in early-life environmental factors, such as improved early-life nutrition or overnutrition, or fewer early-life infections may lead to accelerated growth patterns in contemporary children. Accelerated growth, in turn, may overload the β-cells and/or trigger an autoimmune process in genetically predisposed individuals, thus resulting in an earlier presentation with type 1 diabetes.

### Type 2 Diabetes

Since type 2 diabetes in youth is relatively new and relatively rare, there are limited data on genes associated with early-onset type 2 diabetes (135). Progress in Diabetes Genetics in Youth (ProDiGY), a multi-ethnic collaboration of the Treatment Options for Type 2 Diabetes in Adolescents and Youth (TODAY), SEARCH, and T2D-GENES consortia, conducted the first genome-wide association study (GWAS) in youth-onset type 2 diabetes (136) and identified both known and novel loci. The majority of variants and directions of association were consistent between adults and youth with type 2 diabetes. Many studies show a strong family history among affected youth, with 45%–80% having at least one parent with diabetes and 74%–100% having a first or second degree relative with type 2 diabetes (89). Therefore, genetic factors are likely to play an important role in the risk for type 2 diabetes in youth. However, family history does not always imply a genetic cause, as factors such as similar environmental influences within families and the effects of the intrauterine environment on the offspring also demand consideration. Additional information can be found in the Diabetes in America article Genetics of Type 2 Diabetes (137).

#### Puberty, Obesity, Diet, and Physical Activity

In adults, the risk of type 2 diabetes increases with increasing weight (138), weight gain (139), BMI (138), waist-to-hip ratio (140), and central fat deposition (141,142). In a large study of Danish men, Bjerregaard et al. found that overweight or obesity in childhood (before age 7 years) or during the pubertal period (age 7–13 years) conferred a higher risk of type 2 diabetes, even if remission to healthy weight was achieved after age 13 years (143). Overweight and obesity during childhood and the pubertal period appear to be crucial risk factors for type 2 diabetes in the teenage years, which has been substantiated in other large population-based studies (144,145,146).

Puberty is a state of significant physiologic insulin resistance, on par with that seen during pregnancy (147,148,149,150). When pubertal insulin resistance is overlayed on obesity-associated insulin resistance, akin to gestational diabetes, some youth cannot increase insulin secretion sufficiently (149,151) and glucose rises into the ranges currently defined as prediabetes or type 2 diabetes.

The rise in type 2 diabetes in youth has paralleled the increasing prevalence of overweight and obesity in North American youth and worldwide. Data from the NHANES indicate that between 2017 and 2020, 21.8% of boys and 19.2% of girls age 12–17 years had BMI z-scores consistent with obesity compared to 17.8% of boys and 17.2% of girls in 1990–2000 (152). The prevalence of obesity was highest among non-Hispanic Black (23.9%), non-Mexican American Hispanic (17.6%), and Mexican American (17.5%) youth relative to non-Hispanic White youth (13.1%). The COVID-19 pandemic increased behaviors that accelerated weight gain in children, including increased screen time, stress, lower physical activity, and less access to healthy foods. The CDC utilized data from IQVIA’s Ambulatory Electronic Medical Records database to compare longitudinal trends in BMI in a large cohort of adolescents age 2–19 years before and during the pandemic (153). Between the prepandemic and pandemic periods (January 1 2018–February 29, 2020 and March 1, 2020–November 30, 2020, respectively), the rate of BMI increase approximately doubled, from 0.052 to 0.100 kg/m^2^/month (ratio 1.93, 95% CI 1.90–1.96). The proportion of youth in this national care-seeking cohort increased from 19.3% to 22.4% in 1 year. The youth with overweight or obesity before the pandemic experienced significantly higher rates of increase than those with healthy BMIs, with rates of increase of 0.06, 0.10, and 0.18 kg/m^2^/month for those with overweight, moderate obesity, and severe obesity, respectively, compared to 0.03 kg/m^2^/month for youth with healthy BMIs. This result mirrors findings from Kaiser Permanente Southern California and Children’s Hospital of Philadelphia (154,155). The COVID-19 pandemic negatively influenced the lives of children, with a disproportionate burden on the most vulnerable living in disadvantaged families due to loss of family income, lack of in-person education, decline in mental well-being, decreased dietary quality, lower physical activity levels, and increasing screen time (156).

Obesity is likely linked to changes in children’s diets (157,158). Fast food and high-fat/high-sugar food consumption have increased, while time for family meals has decreased in many societies. Childhood obesity trends have been attributed to several dietary factors, including consuming food outside the home, increased portion sizes, intake of sugar-sweetened beverages, and increases in snacking behaviors. An analysis of dietary patterns in 49,952 U.S. children age <19 years from eight nationally representative surveys found a signiﬁcant increase in the per capita energy intake derived from snacks between 1977 and 2014, with the largest increase among children from the lowest income and education households. The overall calorie intake from snacking was 459 kcal d^-1^, with the bulk coming from desserts, sweets, sugar-sweetened beverages, and salty snacks. While diet composition may contribute to obesity, the most important aspect in the development of type 2 diabetes in youth is likely to be excess caloric intake relative to caloric expenditure. In 2012–2013, the Healthy Hunger-Free Kids Act (HHFKA) was legislated by the U.S. Congress, which improved meal patterns (frequency and overall composition of food types) and nutritional standards for the National School Lunch and School Breakfast Program (159). Because this program reaches 31 million students in 99% of U.S. public schools, it has the potential to affect the nutritional health of children.

Concurrent with changes in diet, physical activity has decreased among children and adolescents (160). In the Youth Risk Factors Surveillance Survey in 2023, only 24.6% of high school students surveyed had participated in at least 60 minutes per day of physical activity (161), with significantly lower estimates for females (16.6%) relative to males (32.2%) (162). One reason for the decline in physical activity is the reduction of physical education in schools, with participation rates down from 41.6% in 1991 to 24.5% in 1995, 31% in 2011, and 27.4% in 2023 (162,163,164). In the developed world, increasing use of computers and television have been associated with decreasing children’s activity level (158,165), as have a lack of safe places to play, lack of organized sports, and fewer children walking to school. Meta-analyses have shown that physical activity interventions can substantially benefit insulin sensitivity in children and adolescents, particularly those with vigorous- to moderate-intensity levels associated with play and sports (166).

#### Early-Life Factors

While postnatal lifestyle is the most immediate cause of obesity, the intrauterine environment is increasingly recognized as an important contributor to disease both in childhood and in adult life. The influence of the maternal in utero environment is evidenced in the U- or J-shaped relationship between birth weight and adult obesity and metabolic disease, demonstrating that both nutritionally limited and excessive in utero environments can lead to postnatal obesity and type 2 diabetes (167,168). Developmental biology has revealed the role of a mismatch between a constrained prenatal and a plentiful postnatal environment in the pathogenesis of obesity, i.e., “thrifty” obesity pathway (169). This is likely operating in developing countries and populations undergoing rapid transition. Another developmental pathway to obesity, likely more important in Western societies, is the fetal overnutrition pathway, resulting from exposure to maternal diabetes and/or obesity in utero. This pathway reflects the effects of hypernutrition during fetal life and creates the conditions for the later pathophysiologic effects of an obesogenic environment (169). Both genetic and environmental factors are likely to be involved in mediating these relationships.

##### Fetal Overnutrition

Exposure to maternal diabetes in utero is a significant risk factor for obesity, impaired glucose tolerance, and type 2 diabetes in youth (170). The offspring of women with diabetes during pregnancy have more obesity during childhood and adolescence than those without diabetes during pregnancy, as demonstrated by the longitudinal follow-up of offspring of Pima Indian women with diabetes (171,172,173). The offspring of women with diabetes were large at birth, and at every age before 20 years, they were heavier for height than the offspring of women with prediabetes or women without diabetes. Consequently, at every age before 20 years, the offspring of Pima Indian women with diabetes had more type 2 diabetes than those of women with prediabetes and women without diabetes (174). The higher prevalence of type 2 diabetes was only partially mediated by the earlier development of obesity in these offspring (175).

While intrauterine exposure is often difficult to separate from genetic factors, obesity and type 2 diabetes in the offspring of mothers with diabetes are not solely due to genetics. To determine the role of exposure to the diabetic intrauterine environment while controlling for genetic susceptibility, mean BMI and prevalence of type 2 diabetes were compared in Pima Indian siblings age <20 years born before and after their mother developed diabetes (176). BMI was significantly higher (+2.6 kg/m^2^) in the 62 siblings born after their mothers were diagnosed with type 2 diabetes (exposed to the diabetic intrauterine environment) than in the 121 age-matched siblings born before. Similarly, within the same Pima Indian family, siblings born after the mother’s diagnosis of diabetes had more than a threefold higher risk of developing diabetes at an early age than siblings born before the diagnosis of diabetes in the mother (odds ratio [OR] 3.7, p<0.02).

Among Pima Indian youth, exposure to maternal diabetes and obesity in pregnancy accounted for most of the dramatic increase in type 2 diabetes prevalence over the previous 30 years (20). A similar finding was seen in other race/ethnicity groups (non-Hispanic White, non-Hispanic Black, and Hispanic), where exposure to maternal diabetes and obesity together contributed to 47% of type 2 diabetes in the offspring (177). Thus, increasing exposure to maternal diabetes during the intrauterine life may be an important contributor to the increasing incidence of youth-onset type 2 diabetes observed in North American studies.

##### Breastfeeding

In population-based studies, breastfeeding is protective against the later development of obesity and type 2 diabetes (178,179). In Pima Indians, exclusive breastfeeding for the first 2 months of life protected against the development of type 2 diabetes in adolescence and young adulthood (OR 0.64, 95% CI 0.4–0.9) (180), which was also seen in a group of youth of diverse racial and ethnic backgrounds (181). The prevalence of having been breastfed (any duration) was lower among youth with type 2 diabetes than among controls, and having been breastfed was associated with significantly lower odds of type 2 diabetes (OR 0.26, 95% CI 0.15–0.46). Thus, for the offspring of pregnancies that carry a high risk for future obesity, early infant diet may represent an opportunity to influence long-term consequences. Of note, the Exploring Perinatal Outcomes among Children (EPOCH) study in Colorado demonstrated that offspring who were exposed to maternal gestational diabetes and were breastfed for ≥6 months had lower overall and central adiposity measures at an average age of 10 years compared to those breastfed for <6 months (182). Taken together, these data suggest that breastfeeding may also attenuate the increased risk of type 2 diabetes associated with in utero overnutrition; this hypothesis requires further testing.

## Complications of Diabetes in Youth

In children and adolescents with diabetes, acute complications are generally more common than chronic complications during these early years, and at this age, they carry a greater relative risk of morbidity and mortality (183). Over a longer time horizon, however, chronic complications become more prevalent, particularly as youth with diabetes transition into adulthood. Data on both acute and chronic complications are essential for evaluating the effectiveness of diabetes education and management programs and identifying subgroups at increased risk. Landmark studies, such as SEARCH and TODAY, have documented the burden of complications in youth with diabetes, with excess burden in those with type 2 diabetes and in youth of race/ethnicity other than non-Hispanic White with type 1 diabetes (184,185). Importantly, accumulating evidence has demonstrated that youth with type 2 diabetes experience a more aggressive disease course than youth with type 1 diabetes, leading to earlier onset and faster progression of chronic complications in adulthood.

This section summarizes data on acute and chronic complications observed during childhood and adolescence in North American youth, with comparisons between youth with type 1 and type 2 diabetes. Data from select contemporary studies are presented in the tables.

### Acute Complications

The major acute complications of diabetes in youth are DKA and hypoglycemia. Table 1 summarizes studies of the occurrence of DKA and hypoglycemia in North American youth with diabetes.

#### Diabetic Ketoacidosis

DKA is a serious, costly, and potentially preventable complication caused by insulin deficiency. If left untreated, it can lead to coma and death. DKA may be present at clinical presentation of both type 1 and type 2 diabetes and can also occur in individuals with established diabetes. The biochemical criteria for the diagnosis of DKA usually include hyperglycemia (blood glucose >11 mmol/L [>200 mg/dL]) with a venous pH <7.3 and/or a bicarbonate level <15 mmol/L. Glycosuria, ketonuria, and ketonemia are also present. These criteria are reasonably standardized across multiple studies.

##### Type 1 Diabetes

Clinic-based (186,187,188) and population-based (40,189,190,191,192) studies have reported a prevalence of DKA at the onset of type 1 diabetes ranging from 25% to >30% across ages 0–19 years. DKA prevalence is higher at younger ages (<5 years) (40,186,187,188), and higher prevalence is usually associated with diverse racial and ethnic backgrounds, lower family income and education, and lack of health insurance (40,189,190,191,192). The T1D Exchange Clinic Registry found that after adjustment for socioeconomic status, more non-Hispanic Black participants experienced DKA events in the previous year than non-Hispanic White or Hispanic participants (both p<0.001) (193,194).

In a cohort of 1,243 pediatric patients with established type 1 diabetes from the Denver, Colorado, metropolitan area, the incidence of DKA after diagnosis ranged from 4 to 12 per 100 person-years between 1996 and 2000 (195). Data from the T1D Exchange Clinic Registry of >13,000 youth with type 1 diabetes across the United States found a similar prevalence of at least one episode of hospitalization for DKA in the past year (194). The Registry also found higher DKA rates among females, those with higher A1C, non-White race, lower income, and lack of private insurance (194). The Diabetes Control and Complications Trial (DCCT) randomized participants with type 1 diabetes to intensive (multiple daily insulin injections or pumps) or conventional care. Among adolescents in the trial, intensive glycemic management decreased the incidence of DKA by approximately 40% (p=0.17) (196), although absolute rates were only 2.8 (intensive) and 4.7 (conventional) per 100 person-years in trial participants, lower than in the general population with type 1 diabetes. SEARCH reported that the rates of acute complications, emergency department visits, and hospitalizations were lower among youth using insulin pumps compared to all other regimens (197), and no increase in DKA was seen among pump users in the T1D Exchange Clinic Registry (194).

In Europe, large decreases in the prevalence of DKA at the onset of diabetes have been reported from Sweden (198) and Finland (199,200) from the late 1970s to the mid-2000s. These countries had programs directed at increased DKA awareness, which may partially explain the changes, since no such trends were reported from Germany or Austria (201,202,203) over a similar period. In addition, in a study compiling longitudinal data from multiple national and international registries in youth with type 1 diabetes (age ≤18 years), Zimmermann et al. found that rates of DKA decreased globally from 3.1 per 100 person-years in 2013 to 2.2 per 100 person-years in 2022 (204).

In contrast, no significant changes in overall DKA hospitalization rates from 1991 to 1999 were seen in Ontario, Canada, youth age 0–19 years, with the highest rates reported in the 15–19-years age group (205), and an increase was reported in older youth from Newfoundland and Labrador, Canada (206). Consistent with results from the Pediatric Diabetes Consortium (207), SEARCH reported that the frequency of DKA at the onset of type 1 diabetes remained unchanged at ~30% of U.S. youth from 2002 to 2010 (39). In this study, DKA continued to occur at relatively high rates, especially in younger new-onset persons and those who were socially disadvantaged. In a follow-up report by SEARCH (2010–2016), Jensen et al. observed that DKA at or near diabetes diagnosis increased at a rate of 2% per year in youth-onset type 1 diabetes (208). During this time frame, ~40% of participants with type 1 diabetes presented with DKA at or near to the time of diagnosis, an increase from the previously estimated prevalence of ~30% in 2002–2010 (39). SEARCH data were also used in a multinational study of trends in DKA at diabetes diagnosis occurring from 2006 to 2016 (209). The combined prevalence of DKA was 29.2% for all countries; however, the United States had one of the highest rates (36.9%) and was one of the few countries to have a rising trend (209).

Interestingly, Elding Larsson et al. reported on the DKA prevalence at onset among youth participating in TEDDY in four countries (United States and three in Europe) (210). TEDDY closely monitors children at high risk for type 1 diabetes over time, and DKA prevalence at onset was about one-half of that reported in population-based registries in the same countries where TEDDY is conducted (210,211). Thus, programs of early risk identification and DKA awareness hold promise to reduce the frequency of this complication at diabetes onset.

SEARCH reported on the presence of DKA at diagnosis and its association with less favorable A1C trajectories over time (212). Duca et al. observed that the 28% of youth with type 1 diabetes (n=1,396) who presented with DKA at the time of diagnosis were more likely to be of diverse racial and ethnic backgrounds, to be uninsured or have government-subsidized health insurance, and to have lower household income than youth without DKA at diagnosis (72%) (212). In addition, the presence of DKA at diagnosis was associated with worsening A1C trajectories over time, independent of demographic (sex, race/ethnicity, age at diagnosis), socioeconomic (household income, insurance status), and diabetes-related factors (frequency of glucose monitoring, insulin regimen, residual insulin secretion at diagnosis) (212).

##### Type 2 Diabetes

Youth with type 2 diabetes can also present in DKA, with reported frequencies of 5%–29% (22,40,41,213,214). A lower prevalence (4.2% at age 0–18 years) in First Nation Canadian youth with type 2 diabetes has been reported (42). Youth with type 2 diabetes may also present with hyperglycemic hyperosmolar nonketotic coma, a life-threatening complication marked by severe hyperglycemia, dehydration, and altered mental status, without ketosis (215,216). SEARCH found that DKA in youth with type 2 diabetes was more frequent in non-Hispanic Black and Hispanic youth than in non-Hispanic White youth (39), consistent with results from other studies (22,41,213). DKA in youth with type 2 diabetes was also associated with lower family income and parental education and less health insurance, independent of race/ethnicity (40). From 2002 to 2010, DKA prevalence at the onset of type 2 diabetes declined from 11.7% to 5.7% (p-value for trend=0.005) (39).

During the COVID‑19 pandemic, youth with newly diagnosed diabetes, both type 1 and type 2, experienced significantly higher rates of DKA at presentation (pooled IRR 1.26) compared with before the pandemic (217). Among youth with new-onset type 2 diabetes, the proportion presenting in DKA rose sharply to about 20% in 2020 compared to under 10% in prior years (218).

#### Hypoglycemia

Severe hypoglycemia in large population-based studies is based on self or family report of requiring assistance, which may include seizure or loss of consciousness, and/or use of an emergency department or hospitalization (219,220,221). Rarely are concurrent glucose levels measured nor are they required to meet the definition of severe hypoglycemia. In youth with diabetes, caregivers may aid treatment across a spectrum of hypoglycemic episodes; therefore, understanding whether cognitive impairment is present is crucial in identifying a severe hypoglycemic episode.

##### Type 1 Diabetes

Before the introduction and widespread use of continuous glucose monitoring (CGM) and automated insulin delivery systems, severe hypoglycemia occurred in 4%–35% of children with type 1 diabetes each year (195,222,223,224). In the landmark DCCT study, the overall rate of severe hypoglycemia for adolescents in the conventional treatment group was 27.8 per 100 person-years and 9.7 per 100 person-years for events leading to seizure/coma (196). During the DCCT, adolescents experienced higher rates of severe hypoglycemia and were more likely to have suboptimal glycemia than adults (225). Interestingly, participants who entered the DCCT as adolescents between 1983 and 1989 continued experiencing severe hypoglycemia more often than adults during 20 years of observational follow-up in the Epidemiology of Diabetes Interventions and Complications study (EDIC; 1994–2014) (226). In the 10–20 years following the DCCT, similar rates were observed across the United States (194,195,223).

More recent data from SEARCH and other studies have demonstrated a reduction in the rate of severe hypoglycemia among youth with type 1 diabetes. In SEARCH, the prevalence of one or more episodes of hypoglycemia in the past 6 months was reported to be 7.0% in 2011–2015 among 2,399 participants with a mean diabetes duration of 8.0 years (227). Compared to participants without any events, those with one or more events were older, were more likely to have obesity or be physically active, and had lower A1C levels. A 1-unit increase in A1C was associated with a 16% lower likelihood of reporting an event, while being physically active was associated with an 87% higher likelihood of reporting an event (227). There were no significant differences by race/ethnicity. In addition, in a 2025 study compiling longitudinal data from multiple national and international registries in youth with type 1 diabetes (age ≤18 years), Zimmermann et al. found that rates of severe hypoglycemia decreased globally from 3.0 per 100 person-years in 2013 to 1.7 per 100 person-years in 2022 (204). These reductions paralleled increases in the use of insulin pumps (42.9% in 2013 to 60.2% in 2022) and CGM (18.7% in 2016 to 81.7% in 2022) (204).

For children age <8 years, use of real-time CGM has been shown in clinical trials to lower time in hypoglycemia, defined as mean time with glucose <70 mg/dL (<3.89 mmol/L), compared to youth randomized to blood glucose monitoring (228). Pediatric registry data have demonstrated reduced rates of severe hypoglycemia within the first year of CGM use (229,230). Further, use of subsidized CGM by youth reduced the absolute rate of severe hypoglycemia from 10.7 events per 100 person-years to 6.8 events per 100 person-years at 24 months post-CGM start (OR 0.59, 95% CI 0.48–0.78, p<0.001) (231).

Some differences between studies may be definitional, with higher rates in studies including “requiring assistance” as part of the definition and lower rates in studies based only on loss of consciousness or seizure. Importantly, in studies of youth before the adoption of CGM, 73% of documented hypoglycemic episodes occurred in the absence of symptom recognition by the child and their parents (232). Hypoglycemia unawareness, a condition more common in those achieving glycemic targets, longer diabetes duration, and younger age of onset, further increases the risk of severe hypoglycemia (224). Severe hypoglycemia leading to seizure/coma in youth with type 1 diabetes has been linked with cognitive dysfunction and abnormalities in brain structure (233,234,235), as well as with mortality (236,237).

In recent years, clinical care has been vastly transformed by the commercialization of automated insulin delivery systems, which algorithmically modulate insulin delivery based on sensor glucose data. Clear evidence has emerged from clinical trials showing improvements in glycemia with these systems (238). Importantly, registry data have confirmed the glycemic benefit as measured by lower A1C, reduced glycemic variability, and increased CGM-derived time in target range (time between 70 and 180 mg/dL [3.89–10 mmol/L]), with evidence of no increased risk of severe hypoglycemia with system use (238).

##### Type 2 Diabetes

Systematic reports of population studies of youth with type 2 diabetes and the prevalence or incidence of hypoglycemia are limited. In SEARCH and TODAY, hypoglycemia was rare, even with insulin therapy (185,227,239). Estimates from SEARCH confirmed that severe hypoglycemia was less common in youth with type 2 diabetes than in youth with type 1 diabetes (2.6% vs. 7.0%, p<0.002) (227).

### Microvascular Complications

#### Diabetic Retinopathy

##### Type 1 Diabetes

While a large number of studies of diabetic retinopathy have been conducted worldwide, few are contemporary studies among younger persons with type 1 diabetes in North America. The historic cohorts described here are important because they provide rare, long-term follow-up of youth-onset type 1 diabetes into adulthood, capturing complication rates before modern therapies and serving as a benchmark for evaluating trends, the impact of improved glycemic management, and the natural history of complications. Mean A1C levels (often in the 8.5%–9.5% [69–80 mmol/mol] range in the 1980s–1990s) were substantially higher than those typically reported in more recent type 1 diabetes populations in the United States (e.g., ~8.0% in SEARCH during the 2010s), reflecting differences in available therapies, glucose monitoring technology, and treatment targets.

The Wisconsin Diabetes Registry Study (WDRS, 1990–2002), which followed 474 youth with type 1 diabetes onset at age <15 years, showed that the prevalence of any diabetic retinopathy was 10% at short diabetes durations (3–7 years) and 40% with up to 15 years duration (240). Comparing the WDRS to the pioneering Wisconsin Epidemiologic Study of Diabetic Retinopathy (WESDR, 1979–1980) (241), which was conducted a decade earlier in the same geographic area, diabetic retinopathy prevalence declined in each age/duration group. Similarly, the Pittsburgh Epidemiology of Diabetes Complications (EDC) Study, which followed 906 youth-onset type 1 diabetes participants for up to 30 years, reported a decline in diabetic retinopathy prevalence at 20 years of diabetes duration for cohorts diagnosed in 1975–1980 (26.5%) compared to those diagnosed in 1965–1969 (38%) (242). Similar findings of reduced diabetic retinopathy prevalence in cohorts diagnosed at later times have been reported from Europe (243) and Australia (244,245), after matching on age of onset and diabetes duration. Across all studies, a much higher proportion of youth were on more intensive insulin regimens over time, which likely contributed to the decline (245).

Significant reductions in diabetic retinopathy occurrence and progression were shown in adolescent participants in the intensive insulin therapy group of the landmark DCCT and the follow-up EDIC study compared to those in the conventional treatment group (196,246,247). The adolescents in the intensive group of the DCCT/EDIC had significant reductions in diabetic retinopathy progression at the end of the DCCT, as well as after 4 years of follow-up in EDIC (246). However, after 10 years of follow-up in EDIC (247), the risk differential between the intensive and conventional treatment groups was reduced among adolescents (adjusted hazard reduction 32%, p=0.13), whereas it was maintained in adult participants (adjusted hazard reduction 56%, p<0.0001). In addition, the prevalence of a further three-step progression on the Early Treatment Diabetic Retinopathy Study (ETDRS) scale in EDIC was the same at 10 years of follow-up for adolescents in both treatment groups, while still reduced in adults treated intensively during the DCCT. In the intensive group, 93% of the observed difference in further diabetic retinopathy progression between adolescents and adults was explained by the mean differences in A1C (higher in adolescents) in the DCCT period. This finding indicates that lower A1C during the randomized trial period was an important determinant of the long-term durability of its benefits. Thus, early and sustained glycemic management is crucial in reducing diabetic retinopathy progression among youth with type 1 diabetes.

Following publication of the DCCT results in 1993, the prevalence of diabetic retinopathy in youth with type 1 diabetes decreased worldwide, with studies before 2000 reporting retinopathy prevalence ranging from 14% to 27% and studies after 2000 reporting rates from 3.7% to 6% (184,248). In Australia, Cho et al. reported a decrease in prevalence from 16% in 1990 to 7% in 2006 (n=819, age 11–17 years, diabetes duration 2–5 years) (249). Several studies have also reported differences in retinopathy prevalence across race/ethnicity groups, with higher rates in non-Hispanic Black and Hispanic youth compared to non-Hispanic White youth (184,250). Similarly, differences have been noted with respect to screening for diabetic retinopathy, with non-Hispanic White youth and those with better glucose management more likely to be screened than non-Hispanic Black or Hispanic youth (251).

More recent studies, such as SEARCH (2002–2019), have reported significantly higher rates of retinopathy in youth with type 1 diabetes compared to earlier historical cohorts (Table 2) (252). Notably, the standardized prevalence of retinopathy, defined as mild nonproliferative or worse, more than doubled from 21.0% at a mean diabetes duration of 7.7 years to 52.0% at 12.5 years diabetes duration. Rates were highest among non-Hispanic Black youth. Furthermore, 38.8% of youth with type 1 diabetes progressed to a more severe grade over the mean 4.6 years between the two imaging assessments, while only 4.3% regressed (252). These findings highlight the need for further study of the development, progression, and risk factors for diabetic retinopathy and other chronic complications in contemporary, post-DCCT, more diverse cohorts with youth-onset type 1 diabetes.

##### Type 2 Diabetes

Available data among youth with type 2 diabetes are summarized in Table 2. The SEARCH study of 1,710 youth with type 1 diabetes and 267 youth with type 2 diabetes (mean diabetes duration 7.9 years in both groups) found a higher age-adjusted prevalence of retinopathy among participants with type 2 diabetes compared to those with type 1 diabetes (9.1% vs. 5.6%) (184,253). Higher estimates (42% vs. 17%) were previously observed in a pilot study (254). Youth of race/ethnicity other than non-Hispanic White with type 1 and type 2 diabetes had more diabetic retinopathy than non-Hispanic White youth; this difference was not explained by glycemia, suggesting that socioeconomic factors related to race/ethnicity might play a role (184). Initial estimates from these SEARCH reports excluded cases of background retinopathy (e.g., microaneurysms only). More recent data from SEARCH included cases of background diabetic retinopathy among youth with type 2 diabetes (252). At a mean diabetes duration of 7.5 years, the standardized prevalence of retinopathy was 31.0%, which increased to 55.7% at 12.4 years diabetes duration. Over the mean 4.4 years between the two imaging assessments, 41.3% of youth with type 2 diabetes progressed, while 5.0% regressed; 3.1% of participants had evidence of proliferative retinopathy (252).

Similarly, retinal photographs were taken at two time points during the TODAY study: in the last year of the trial and again 7 years later during observational follow-up (255,256). The prevalence of any diabetic retinopathy increased from 13.7% to 49.0% over the 7 years, with 25.3% of participants progressing three or more steps on the ETDRS scale; no sex or race/ethnicity differences were observed (256). Unlike SEARCH, only 5% of participants progressed to more advanced states of retinopathy, including severe nonproliferative diabetic retinopathy or proliferative diabetic retinopathy, despite being ~25 years of age (256). Notably, the high prevalences of diabetic retinopathy reported in the SEARCH and TODAY studies (55.7% and 49.0%, respectively) were almost twice the 28.5% prevalence reported using fundus photography in a nationally representative sample of adults with diabetes age ≥40 years (mean diabetes duration 15 years) from the NHANES 2005–2008 (257).

In Manitoba, Dart et al. linked clinical and healthcare administrative data and found that youth with type 2 diabetes had a similar prevalence of retinopathy (11.7%) to those with type 1 diabetes (13.8%) (258). These estimates are lower than those reported in SEARCH and TODAY, most likely because the study was based on clinical examination and diagnostic coding, which likely underestimate background asymptomatic retinopathy.

Among Pima Indians, youth with type 2 diabetes onset at age <20 years had an incidence rate of diabetic retinopathy of 9.7 per 1,000 person-years after 5–10 years of duration; rates among youth-onset type 2 diabetes were 60% lower at every duration than those in persons with later onset of diabetes at age 40–59 years (259).

Outside North America, similar to the Canadian cohort, Constantino et al. found no differences in the prevalence of retinopathy between youth with type 1 and type 2 diabetes in Sydney, Australia (n=470, 41% vs. n=354, 37%, respectively, p=0.30) at an average 11–15 years of diabetes duration (260). Alternatively, the SWEDIABKIDS study reported a significantly higher risk of retinopathy in youth with type 2 diabetes compared to youth with type 1 diabetes (n=130, 24.6% vs. n=499, 19.2%, respectively, p=0.01) at a mean diabetes duration of 5–7 years (261).

In terms of potentially modifiable risk factors, the SEARCH study reported significant associations between elevated A1C, systolic and diastolic blood pressure, and higher BMI with diabetic retinopathy (252). Similarly, in TODAY, compared to those who did not progress, participants who progressed had significantly lower BMI, higher A1C, higher blood pressure, increased triglycerides, decreased C-peptide, and higher prevalences of hypertension and kidney disease (256). No significant differences by sex or race/ethnicity were observed. In Pima Indians, longer duration, higher A1C, and presence of macroalbuminuria were associated with the development of retinopathy (262).

#### Diabetic Kidney Disease

The spectrum of diabetic kidney disease typically starts with low levels of albumin in the urine (“moderately increased albuminuria,” usually 20–200 μg/min albumin excretion rate [AER] or albumin:creatinine ratio [ACR] 30–300 μg/mg), progresses through severely increased albuminuria (usually AER ≥200 μg/min or ACR >300 μg/mg) to kidney impairment (marked by falling glomerular filtration rates [GFR] and rising serum creatinine concentrations) and kidney failure requiring dialysis or kidney transplant. A subset (15%–20%) of individuals with diabetes and kidney failure do not progress through a proteinuria phase (nonproteinuric [normoalbuminuric] kidney disease) (263,264,265). Among youth, the later stages of kidney impairment and kidney failure are rare, largely due to their young age and typically shorter duration of diabetes. These more advanced stages of kidney disease are more commonly observed in adulthood, while in youth, the early progression of moderately increased to severely increased albuminuria is usually observed. Studies of kidney disease in North American youth are summarized in Table 3.

##### Type 1 Diabetes

In the United States, between 2001 and 2003, SEARCH reported a prevalence of a single elevated ACR (≥30 µg/mg) of 9.2% among a large cohort of youth with type 1 diabetes after a mean diabetes duration of 3.7 years (n=2,885, onset age <20 years) (266). Nearly a decade later, the T1D Exchange Clinic Registry reported a prevalence of persistent (or sustained) moderately increased albuminuria (ACR ≥30 mg/g) of 4.4% from another large cohort of youth with type 1 diabetes (n=7,549, onset age <20 years, mean diabetes duration 6.5 years) (267). This apparent discrepancy may be ascribed to the use of a single elevated ACR in SEARCH, rather than a sustained level as required by the T1D Exchange Clinic Registry, or a demographically dissimilar study group, including different proportions of youth with longer duration, older age, or worse glycemic control. In Canada, Dart et al. reported a prevalence of persistent moderately increased albuminuria among Manitoba youth with type 1 diabetes of 12.7% (n=1,011, mean age at baseline 8.9 years, mean diabetes duration 6.3 years), with 1.6% having persistent severely increased albuminuria and 1.4% already in kidney failure (268).

These estimates are consistent with older reports from the 1980s and 1990s. In the WESDR, the 10-year incidence of renal insufficiency rose from 5.6% among those with 0–9 years of diabetes duration to 15.2% for 10–14 years, then stabilized until ≥35 years, when the cumulative incidence was 33.5% (n=756) (269). Similarly, in the Pittsburgh EDC Study (n=627, onset age <17 years), at an average diabetes duration of 20 years, the prevalence was 22% for moderately increased albuminuria and 27% for severely increased albuminuria (270). Interestingly, in the EURODIAB Complications Study (n=1,215, onset age <36 years), while the prevalence of moderately increased albuminuria was similar to that of the Pittsburgh EDC Study (25%), the prevalence of severely increased albuminuria was about one-half (12%) of the prevalence in the EDC and was not explained by differences in factors known to influence albuminuria (hypertension, treatment, A1C, age, diabetes duration, smoking, sex) (271).

Moderately increased albuminuria does not necessarily portend progressive kidney disease and regresses to normal albumin levels (normoalbuminuria) in at least one-third of cases. In adults with youth-onset type 1 diabetes, Perkins et al. found that the 6-year cumulative incidence of regression of moderately increased albuminuria (defined as a 50% reduction in urinary albumin excretion from one 2-year period to the next) was 58% (272). Similarly, in youth with type 1 diabetes (n=462, onset age <17 years, mean diabetes duration 7.6 years), the 10-year cumulative incidence of regression was 47.6% (273). Since moderately increased albuminuria is associated with insulin resistance (270) and predicts not only kidney disease but also macrovascular events and total mortality (274), it may not be surprising that fluctuations and regression would be associated with improved levels of glycemia and cardiovascular risk factors (275,276).

The T1D Exchange Clinic Registry found that older age, female sex, longer diabetes duration, higher mean A1C, higher diastolic blood pressure, and lower BMI (potentially ascribed to poor glycemic control) were significantly associated with moderately increased albuminuria (267). Lowering of A1C by more intensive insulin treatment has been rigorously shown to reduce kidney disease by the DCCT/EDIC study (277). Among adolescents at the end of the DCCT, there was a 10% relative risk reduction for kidney disease in the primary prevention cohort (diabetes duration <6 years, AER <40 mg/24 hours at randomization) and a 55% relative risk reduction in the secondary prevention cohort (diabetes duration 1–15 years, AER <200 mg/24 hours at randomization) (196). Four years after the end of the DCCT during the EDIC follow-up (246), among those free of moderately increased albuminuria at DCCT closeout, the relative risk reduction was 48% for the development of moderately increased albuminuria and 85% for the development of severely increased albuminuria (246). Thus, for youth and young adults, improved glycemic management early in the natural history of type 1 diabetes reduces the risk of developing both moderately increased and severely increased albuminuria. Likewise, data from the WESDR demonstrated significant associations between older age, higher A1C, and hypertension and kidney impairment (269).

##### Type 2 Diabetes

Kidney disease is a prominent and rapidly progressing complication in youth with type 2 diabetes. Data from Indigenous populations (Pima Indians, Arizona; First Nation, Manitoba), as well as multiethnic cohort studies, such as SEARCH and TODAY, highlight the aggressive nature of kidney disease in this population. Key markers of early kidney disease include moderately elevated albuminuria and glomerular hyperfiltration. In youth with type 2 diabetes, the prevalence of moderately increased albuminuria ranges from 8% to 30% within the first 10 years of diagnosis (184,185,266,278). A systematic review of 16 studies reported a pooled prevalence of 21.6% for moderately increased albuminuria in youth with type 2 diabetes (n=2,441, age 7.1–20.0 years, duration diagnosis to 7.8 years) (279), with higher rates in Pacific Islander, Indigenous, and Asian youth compared to non-Hispanic White youth (31.8%, 24.3%, 23.0%, and 12.6%, respectively), but no sex differences were observed. Cioana et al. also reported a pooled prevalence of 29.2% for persistent moderately increased albuminuria, defined as two of three samples, in 10 studies with 1,345 participants (279).

Among Pima Indian youth in Arizona, one of the highest-risk populations for type 2 diabetes, kidney disease is common, with the prevalence of moderately increased albuminuria reaching nearly 30% within the first 5 years of diabetes onset (280). Similar estimates at diagnosis or within 1–2 years have been reported in other North American studies (266,268). Data from Manitoba show that Indigenous youth with type 2 diabetes have an alarming rate of kidney complications, with an estimated 26.9% of youth having persistent moderately increased albuminuria after only 1.6 years of diabetes duration (mean age 14.9 years) (268). Furthermore, Dart et al. reported that in this group of 342 youth with type 2 diabetes, 6.7% experienced kidney failure over a mean follow-up of 5.3 years (9.1% among those with persistent albuminuria vs. 1.1% among those without albuminuria) (268). This high burden of kidney disease in First Nation youth may be partially attributed to population-specific genetic factors that influence susceptibility, for example, HNF1A and AGT variants. Additionally, social determinants of health, including the intergenerational effects of colonization and racism, poverty and food insecurity, overcrowded/poor‑quality housing, and limited access to preventive and specialty nephrology care in rural and remote communities, are major drivers of early chronic kidney disease onset and progression in First Nation youth.

In TODAY, moderately increased persistent albuminuria (ACR ≥30 µg/mg) was documented in 18.0% of participants after a mean follow-up of 3.9 years, with persistent glomerular hyperfiltration (eGFR ≥140 mL/min/1.73 m^2^) affecting up to 13.3% of youth during the early disease stages (281). Longitudinal data from the TODAY2 study, the long-term observational follow-up of the TODAY cohort, demonstrated that after an average follow-up of 10.2 years, the 15-year cumulative incidence of moderately increased albuminuria was 54.8% (n=500, mean age at follow-up 26.4 years, diabetes duration 13.3 years) (185).

Glomerular hyperfiltration, an abnormally elevated GFR, is common early in youth-onset type 2 diabetes. In the TODAY cohort, youth with the highest peak eGFR over follow-up had the greatest albuminuria burden at 10 years, linking hyperfiltration to subsequent kidney injury (282). SEARCH data showed that eGFR decline is more common in type 1 diabetes, whereas eGFR rise is more common in type 2 diabetes over the first decade of diabetes (283). Mechanistically, hyperfiltration likely reflects intrarenal hemodynamic dysregulation, as well as a distinct molecular program that is associated with the progression of diabetic kidney disease (278,284).

Notably, prevalence estimates for kidney disease in youth with type 2 diabetes are two to five times those observed in youth with type 1 diabetes or adults with type 2 diabetes (184,185,260,266,268,285). In SEARCH, participants with type 2 diabetes versus those with type 1 diabetes had significantly higher odds of kidney disease (ACR ≥30 µg/mg or eGFR ≤60 mL/min/1.73 m^2^) at a mean duration of 7.9 years (19.9% type 2 diabetes vs. 5.8% type 1 diabetes; absolute difference 14.0%) (184). Similarly, in Manitoba, Dart et al. reported that youth with type 2 versus type 1 diabetes had a fourfold increased risk of developing kidney failure, adjusted for age at diagnosis, A1C, BMI, and year of diagnosis (268). A follow-up study linking clinical data to Manitoba electronic health records for a 25-year follow-up found that 2.3% of youth with type 2 diabetes had used dialysis compared with none of the youth with type 1 diabetes, and 8.9% of youth with type 2 diabetes had electronic health record evidence of any kidney complication versus 2.7% of youth with type 1 diabetes and 0.6% of 1,700 youth without diabetes (258). In Pima Indians, youth who developed type 2 diabetes before age 20 years had a fivefold increased risk of kidney failure by middle age and higher mortality rates compared to persons with adult-onset type 2 diabetes (285). Additionally, research kidney biopsies have demonstrated more severe structural kidney injury lesions in participants with youth-onset type 2 diabetes compared to those with adult-onset type 2 diabetes despite similar diabetes durations (286).

Taken together, these data suggest that the risk of kidney disease is substantially higher in youth with type 2 diabetes versus type 1 diabetes at comparable known durations of diabetes. Similar findings were reported by studies outside North America. Japanese and Korean youth with type 2 diabetes onset at age <30 years had almost twice the prevalence of proteinuria at each duration of follow-up compared with youth with type 1 diabetes (287). In a study in New South Wales, Australia, the prevalence of moderately increased albuminuria was 28% in youth with type 2 diabetes and 6% in youth with type 1 diabetes (288).

Severely increased albuminuria, though less common, indicates a more severe progression of kidney damage and is strongly linked to poor metabolic control. In a meta-analysis performed by Cioana et al., the pooled prevalence of severely increased albuminuria from four studies including 730 youth with type 2 diabetes was 3.9% (279), which was similar to the 4.7% prevalence for persistent severely increased albuminuria previously reported by Dart et al. (268). Higher rates were reported among First Nation or Métis youth with type 2 diabetes in Manitoba (16% severely increased albuminuria at 2.5 years duration) (289).

Preliminary data from the initial 5 years of TODAY reported that loss of glycemic management (A1C) and hypertension were associated with an increased risk of developing moderately increased albuminuria and rapid eGFR decline (290), while insulin resistance was associated with an increased risk of glomerular hyperfiltration in youth with type 2 diabetes (281). In addition, females had a threefold greater risk of developing glomerular hyperfiltration (eGFR ≥140 mL/min/1.73 m^2^) over 5 years compared to males (281). Subsequent analyses in TODAY, after an average of 10.2 years of follow-up, demonstrated that A1C, hypertension, dyslipidemia, and baseline serum uric acid were associated with an increased risk of moderately increased albuminuria, while A1C independently increased the risk of persistent glomerular hyperfiltration (eGFR ≥135 mL/min/1.73 m^2^) and rapid eGFR annual decline (eGFR >3 mL/min/1.73 m^2^ and/or ≥3.3%) (291). Ethnic disparities also play a role, with non-Hispanic Black, Hispanic, and Indigenous populations disproportionately affected due to a combination of genetic predisposition and socioeconomic factors (279,291,292). Among the multiethnic U.S. youth enrolled in the SEARCH study, female sex, higher A1C and triglyceride values, and elevated blood pressure were independently associated with moderately increased albuminuria (266).

Another known risk factor for diabetic kidney disease is exposure to maternal diabetes in utero. Among the Pima Indians, the offspring of mothers who had diabetes during pregnancy had significantly higher rates of proteinuria (280) and kidney failure (293) many years later than the offspring of mothers who were normoglycemic or had prediabetes. Among Manitoba youth with type 2 diabetes, 16% had mothers with pregestational diabetes compared with only 2.7% of youth with type 1 diabetes (268). Thus, maternal diabetes may be responsible not only for increasing the risk of type 2 diabetes in youth but also for the increased risk of kidney disease in youth with type 2 diabetes due to the earlier onset of diabetes in those with in utero exposure. The increased kidney disease risk may also be attributed to reduced nephron mass in offspring exposed to maternal diabetes during pregnancy, as these types of pregnancies are associated with both small and large for gestational age births, conditions that are themselves risk factors for kidney disease.

These findings emphasize the urgent need for early intervention strategies targeting glycemic control, blood pressure management, and lifestyle modifications to mitigate the high burden of kidney disease in young persons with type 2 diabetes. Addressing health disparities and providing equitable access to care are also critical in reducing long-term complications in this vulnerable population. Sodium-glucose cotransporter-2 (SGLT2) inhibitors are now approved in the United States for pediatric patients with type 2 diabetes age ≥10 years for glycemic management (294,295), but they are often used for their kidney-protective benefits (296), as shown in adult trials (297). Glucagon-like peptide-1 (GLP-1) receptor agonists are similarly approved for youth-onset type 2 diabetes (298) and attenuate hyperfiltration and reduce albuminuria in adolescents with type 2 diabetes (299). Nonsteroidal mineralocorticoid receptor antagonists, such as finerenone, have demonstrated kidney protection in adults with type 2 diabetes (300) but remain understudied in pediatric type 2 diabetes; they are currently being tested in pediatric chronic kidney disease. As always, comprehensive management of glycemia, blood pressure, body weight, and lipids remains central to mitigating kidney risk in this vulnerable group.

#### Neuropathy

The topic of neuropathies in diabetes is complex due to the diverse clinical manifestations and difficulties in definition and measurement methods (301). This section focuses on chronic distal symmetric polyneuropathy and cardiovascular autonomic neuropathy (CAN) in youth with type 1 and type 2 diabetes. Data on neuropathy in North American youth are summarized in Table 4.

##### Diabetic Peripheral Neuropathy

The most common form of diabetic peripheral neuropathy (DPN) is distal symmetrical polyneuropathy, which accounts for approximately 75% of all neuropathies in diabetes and can be classified as primarily small-fiber, primarily large-fiber, or mixed small- and large-fiber (301,302). DPN is a type of nerve damage that typically affects the hands and feet but may eventually progress to the arms and legs. Symptoms of DPN vary by the class of sensory fibers involved and generally include burning, shooting, or stabbing pain, numbness, or tingling without pain (301). These symptoms are often worse at night and usually affect the feet and toes, although in some patients, the hands may be affected as well. Definitive diagnosis of DPN requires motor and sensory nerve conduction studies; however, these tests may be costly, burdensome, and difficult to standardize across multicenter studies. Alternatively, assessments for DPN include comprehensive documentation of symptoms in combination with evaluations of pinprick or temperature sensation (for small-fiber function) or vibration perception (for large-fiber function) (303,304). In addition, the 10-g monofilament test is used to assess for risk of ulceration and amputations.

Type 1 Diabetes

Using a Michigan Neuropathy Screening Instrument (MNSI) examination score >2 to define DPN, SEARCH reported a 7% prevalence of DPN in youth with type 1 diabetes after a mean duration of 7.2 years (n=1,734, mean age 18 years) (305). Earlier studies in European cohorts (288,306) reported much higher rates among similarly aged participants: 62% among Danish participants using vibration perception threshold (VPT) testing (n=339, age 12–27 years, diabetes duration 9–25 years) (306) and 27% among Australian participants using thermal and vibration testing (n=1,433, median age 15.7 years, median diabetes duration 6.8 years) (288). Studies of DPN are difficult to summarize due to substantial differences in measurement methods; therefore, the lower prevalence rate observed in SEARCH may be due to the variation in study outcome definitions used to assess DPN.

Globally, data from the DiaMond DiaComp study demonstrated the notable geographic variation of DPN (sixtyfold) in youth and young adults with type 1 diabetes across 12 countries in Asia, Europe, and North and South America (n=892, mean age 21.5 years, diabetes duration 13.1 years) (307). Prevalence estimates, based on an MNSI examination score >2, were 5.3% among those with short-duration diabetes (5–14 years) and 28.9% among those with long-duration diabetes (15–24 years) (307).

Most studies that have explored risk factors for DPN have found a major role of hyperglycemia. Importantly, reduction of A1C levels can reduce the incidence of DPN, as shown by the DCCT (308), where lower rates of both peripheral and autonomic neuropathy were observed with intensive treatment. The cumulative incidence of confirmed clinical neuropathy at 5 years was 9.6% in the conventional treatment group and 2.8% in the intensive treatment group. At 13–14 years after DCCT closeout, clinical testing was repeated in 1,186 participants; a lower risk of clinical DPN was noted, as well as improved nerve conduction values, in the intensively treated cohort (309). More recently, the SEARCH study confirmed a significant association between poor glycemic management over time and DPN prevalence in youth with type 1 diabetes (305). In addition to elevated A1C, other factors including older age, smoking, hypertension, obesity, increased low-density lipoprotein (LDL) cholesterol and triglycerides, and lower high-density lipoprotein (HDL) cholesterol were significantly associated with a higher prevalence of DPN (305). In SEARCH, the prevalence of DPN was also strongly associated with the duration of diabetes, with a twofold increase in prevalence among those with longer (>10 years) versus shorter (5–10 years) diabetes duration.

Type 2 Diabetes

In the past decade, results from the SEARCH and TODAY studies have provided more thorough insight into the occurrence of DPN in youth with type 2 diabetes and suggest that DPN is more common among youth with type 2 diabetes than those with type 1 diabetes. In SEARCH, the prevalence of DPN, based on an MNSI examination score >2, in youth with type 2 diabetes was 22% (n=258, mean age 22 years, known diabetes duration 7.9 years) (305). Similarly, in TODAY, using the same outcome definition, the prevalence of DPN increased steadily from 3.1% at baseline to 25.4% after an average follow-up of 10.2 years (n=674, mean age 14 years, known diabetes duration <2 years) (310). The 15-year cumulative incidence of DPN in TODAY was 32.4%, with a significantly higher incidence observed among males than females (310). Taken together, the prevalence estimates for DPN in SEARCH (22%) and TODAY (25.4%) are similar to the 21% prevalence previously reported in a small cohort of Australian youth with recent-onset type 2 diabetes (n=68, mean age 15.3 years, known diabetes duration 1.3 years), with DPN defined by thermal and vibration testing on the foot (288).

Factors associated with DPN in youth with type 2 diabetes, include older age, male sex, smoking, higher BMI, longer diabetes duration, and lower HDL cholesterol (305,310). In the TODAY study, poor glycemic management was associated with a higher risk of DPN, with a 15% increase in odds for every 1-unit increase in A1C (310). Furthermore, TODAY demonstrated that decreases in heart rate variability (HRV, a measure of CAN) and pulse wave velocity (PWV, a marker of vascular disease) were associated with an abnormal MNSI. Rates of DPN by race/ethnicity were not significantly different in SEARCH and TODAY (305,310). Similar to the type 1 diabetes cohort in SEARCH, prevalence of DPN was strongly associated with duration of diabetes in the type 2 diabetes cohort, with a twofold increase in prevalence among those with longer (>10 years) versus shorter (5–10 years) diabetes duration (36% vs. 19%).

Lastly, not unlike other reported rates of complications in the SEARCH study (184), the prevalence of DPN among youth with type 2 diabetes (n=258) was more than three times higher than the prevalence in type 1 diabetes participants (n=1,734) with similar age (18–22 years) and known diabetes duration (7–8 years), even after adjustment for glycemic control, obesity, and blood pressure (305). Similarly, Constantino et al. found that peripheral vibration perception thresholds were significantly higher in youth with type 2 diabetes at an average of 11.6 years of known duration than in youth with type 1 diabetes at 14.7 years of duration (n=354, age of onset 15–30 years) (260).

##### Cardiovascular Autonomic Neuropathy

Autonomic neuropathies may affect the cardiovascular, gastrointestinal, and urogenital systems in individuals with diabetes (301,311). CAN is the most frequently studied manifestation of autonomic neuropathy and is an independent predictor of CVD and mortality in adults with type 1 and type 2 diabetes (312,313,314,315). However, little is known about CAN in youth with diabetes. Generally, the earliest sign of CAN is impaired HRV, which may be completely asymptomatic (301). Although cardiovascular autonomic reflex tests (CARTs) remain the gold standard for diagnosing CAN, they may not be readily accessible or feasible in routine clinical practice. Alternatively, time- and frequency-domain measures of HRV have been validated as surrogate measures of CAN in adults with type 1 and type 2 diabetes (316).

Type 1 Diabetes

A systematic review of 19 studies involving 3,943 youth (age range 3–17 years) with type 1 diabetes in Europe, Australia, and the Middle East demonstrated a wide range of prevalence estimates (16%–75%) for abnormal cardiovascular nerve function tests (cardiovascular reflexes, HRV, baroreflex sensitivity), with a pooled prevalence of 28% (317). Differences in rates were likely attributable to the lack of standardized definitions and the varying number of tests used to define CAN. In a more recent study of youth with type 1 diabetes in Australia (n=253, mean age 14.4 years, diabetes duration 7.1 years), the prevalence of CAN defined by indices of HRV increased from 26% to 39% over a mean follow-up of 4.5 years (318). A smaller study in Egypt reported a higher prevalence of CAN (36.7%) among participants with type 1 diabetes (n=60, mean age 15.1 years, diabetes duration 7.9 years) versus controls (n=40) without diabetes (5.0%) (319).

The SEARCH CVD ancillary study reported that overall HRV was lower in youth with type 1 diabetes (n=354) at 9.8 years duration (mean age 18.8 years) compared to healthy youth without diabetes, and there was evidence of both loss of parasympathetic tone and sympathetic overdrive (320). More recent data from the main SEARCH study estimated CAN prevalence (defined as ≥3 of 5 abnormal HRV indices) to be approximately 12% in youth with type 1 diabetes (n=1,646, mean age 18 years, diabetes duration 8 years) (321). In an analysis among participants in SEARCH with longitudinal HRV data (n=864), after an average of 4.6 years of follow-up, youth with type 1 diabetes demonstrated significant worsening of overall HRV and markers of parasympathetic loss, with median changes in parameters ranging from 14.5% to 20.8% (322). In addition, the SEARCH study reported a higher-than-expected co-occurrence of CAN with arterial stiffness (323).

In type 1 diabetes, CAN is associated with poor glycemic control, longer diabetes duration, higher cholesterol/triglyceride levels, higher blood pressure, and microalbuminuria (317,319,320,321,322). Higher BMI, waist circumference, and waist-to-hip ratio have also been shown to be associated with CAN (318,322,324). In SEARCH, youth with A1C ≥7.5% (≥58 mmol/mol) had significantly reduced HRV compared to controls, while youth with optimal glycemic management did not differ from controls in HRV parameters (320). Nevertheless, as shown in the DCCT/EDIC study, CAN abnormalities are responsive to improvement in A1C levels (325).

Type 2 Diabetes

Most of what we know about the natural history of autonomic neuropathy in youth with type 2 diabetes comes from results published by the SEARCH and TODAY studies (321,322,326,327). Using the definition of ≥3 of 5 abnormal HRV indices, CAN prevalence in youth with type 2 diabetes in SEARCH was 17% at 8 years duration (n=252, mean age 22 years) (321). After an average of 4.6 years of follow-up (n=192), youth with type 2 diabetes in SEARCH demonstrated significant worsening of overall HRV and markers of parasympathetic loss, with median changes in parameters ranging from 23.1% to 66.9% (322). In addition, compared to youth with type 1 diabetes, youth with type 2 diabetes had significantly worse HRV at both time points; however, there were no significant differences between type 1 and type 2 diabetes in change over time (322). In TODAY, using a similar definition based on measures of HRV, CAN prevalence in youth with type 2 diabetes was 8.1% after 7 years of follow-up (n=397, mean age 20.7 years, diabetes duration 7.7 years) (326). Although the age and diabetes duration of participants in TODAY and SEARCH were similar, the lower rate observed in TODAY is most likely attributable to participants being enrolled in a clinical trial aimed at improving their glycemic control. Similar to the SEARCH cohort, TODAY participants demonstrated significant worsening of all HRV indices over 5 years (n=304), with median changes in parameters ranging from 10.1% to 50.0% (327). Notably, the prevalence of standard deviation of normally conducted R-R intervals (SDNN) <70 ms, which is associated with a fourfold higher risk of death in adults, rose from 73.0% to 83.5% over 5 years in TODAY (327).

Outside of North America, few small studies have reported on autonomic neuropathy (288,324). In a small prospective study in Australia (n=66), CAN prevalence defined as two or more abnormal HRV measures was 47% in youth with type 2 diabetes (mean age 15.4 years, diabetes duration 1.7 years) compared to 27% in youth with type 1 diabetes (mean age 16.5 years, diabetes duration 8.0 years) (324).

Similar to type 1 diabetes, in youth with type 2 diabetes, CAN is associated with poor glycemic control, longer diabetes duration, higher triglyceride levels, and microalbuminuria (321,322,326,327). In TODAY, CAN was also associated with hypertension and higher PWV carotid-femoral (326). In addition, youth with type 2 diabetes and arterial stiffness in SEARCH had reduced overall HRV and markers of parasympathetic loss compared to those without arterial stiffness (328). In SEARCH, Hispanic and non-Hispanic White participants (29% and 27%, respectively) had higher prevalences of CAN compared with non-Hispanic Black participants (7%) (321); in TODAY, non-Hispanic Black participants experienced a greater decline in parasympathetic function, as indicated by a higher low-frequency to high-frequency (LF:HF) ratio compared to non-Hispanic White participants (327).

### Metabolic Dysfunction-Associated Steatotic Liver Disease

Metabolic dysfunction-associated steatotic liver disease (MASLD), previously known as non-alcoholic fatty liver disease (NAFLD) (329), is now the most common chronic liver disease in adolescents and adults and is closely associated with insulin resistance, overweight/obesity, and type 2 diabetes. There is often a bidirectional association between MASLD and type 2 diabetes (330,331,332). Less is known about MASLD in type 1 diabetes (333). With the increasing rates of childhood obesity in the United States, MASLD in youth with diabetes raises concern for serious health consequences as these individuals age.

Although liver biopsy remains the gold standard for diagnosing and staging liver disease, biomarkers, such as the liver transaminases alanine aminotransferase (ALT) and aspartate aminotransferase (AST), are used as surrogate markers for liver injury; together with age and platelet count, these biomarkers generate the Fibrosis-4 Index (FIB-4), an estimate of scarring in the liver used to evaluate fibrosis in adults. Various noninvasive imaging techniques also allow for a detailed assessment of liver health, including ultrasound to qualitatively assess liver fat and cirrhosis, magnetic resonance imaging (MRI) or computed tomography (CT) to quantitatively assess liver fat, transient elastography (FibroScan®) to measure liver stiffness (fibrosis), and magnetic resonance (MR) elastography to assess liver stiffness. Currently, the only method for assessing liver inflammation directly is liver biopsy. Available data from North America are summarized in Table 5.

#### Type 1 Diabetes

Data on the prevalence of MASLD in youth with type 1 diabetes in the United States are lacking; most available data come from populations in Europe and Asia. Furthermore, prevalence estimates reported globally are highly variable, likely due to the small sample sizes, variations in methods used for diagnosing MASLD, and differences in demographics (race/ethnicity) and clinical characteristics, such as BMI and glycemia. In particular, BMI has been increasing in youth with type 1 diabetes in some countries (334) and likely explains higher rates of MASLD in these regions.

One study from Arkansas Children’s Hospital in Little Rock, Arkansas, compared controlled attenuation parameter (CAP) scores from transient elastography (n=77, mean age 14 years, diabetes duration 5 years) between children with type 1 diabetes with and without obesity and age-matched controls with obesity but without type 1 diabetes (335). Tas et al. found that participants with obesity, regardless of type 1 diabetes status, had similarly elevated CAP scores, both significantly higher than the group without obesity with type 1 diabetes. MASLD, defined as a CAP score ≥241 dB/m was present in 66% of participants with type 1 diabetes and obesity, 71% of controls with obesity, and 17% of participants with type 1 diabetes without obesity (p<0.001), suggesting that MASLD is strongly related to obesity, regardless of the presence of type 1 diabetes (335). In addition, CAP scores were positively associated with weight, BMI, and A1C and negatively associated with HDL cholesterol in youth with type 1 diabetes (335).

Studies at the University of Colorado used MRIs to quantify liver fat in children and adolescents with type 1 diabetes and controls matched by age, BMI, pubertal stage, and physical activity level. Nadeau et al. found no significant differences in intramyocellular lipid and other metabolic markers (waist circumference, HDL, triglycerides) between youth with type 1 diabetes and matched controls, despite youth with type 1 diabetes having peripheral insulin resistance as assessed by hyperinsulinemic euglycemic clamp studies (336). Similarly, Cree-Green et al. found no significant differences in percent body fat, visceral fat, liver fat, ALT, AST, HDL, or triglycerides between youth with type 1 diabetes (mean age 16 years, mean BMI 24 kg/m^2^) and matched controls, despite youth with type 1 diabetes having muscle and liver insulin resistance (337).

Overall, these studies suggest that youth with type 1 diabetes, compared with BMI-matched controls, have less ectopic fat accumulation and fewer metabolic syndrome features, including MASLD. This pattern may reflect a distinct phenotype or a different mechanism of insulin resistance than that seen in youth with type 2 diabetes.

#### Type 2 Diabetes

Studies evaluating MASLD in youth with type 2 diabetes in the United States have generally been limited to measuring liver transaminases as surrogate markers for liver disease. Early work by Nadeau et al. used data from a comprehensive chart review at a pediatric diabetes clinic and reported that 48% of youth with type 2 diabetes had elevated ALT levels, with 35% having ALT levels that were three times the upper limit of normal (338). Another retrospective medical chart review of 57 participants found a high percentage of youth with type 2 diabetes with elevated ALT and AST levels at diagnosis, with significantly higher rates observed in Hispanic versus non-Hispanic Black youth (ALT: 71% vs. 20%, p=0.002; AST: 53% vs. 0%, p<0.001, respectively) (339). In addition, more than one-third of Hispanic youth with type 2 diabetes had ALT levels more than twice the upper limit of normal. Bacha et al. also reported that the prevalence of MASLD (self-reported diagnosis from a physician) was more common in Hispanic versus non-Hispanic Black youth with type 2 diabetes (9% vs. 2%) in the Pediatric Diabetes Consortium Registry, which enrolled participants with type 2 diabetes age <21 years between 2012 and 2018 (340).

In the TODAY study, although AST/ALT levels >2.5 times the upper limit of normal were exclusionary criteria for entry into the trial, liver transaminase levels were collected during follow-up and had increased to more than twice the upper limit of normal in 13% of the cohort after a mean follow-up of 3.8 years (341). The metabolic syndrome (NCEP ATP III definition), a risk factor for MASLD, was present in 76% of the TODAY cohort at baseline and throughout follow-up (342). In addition, elevated ALT/AST levels were more frequent in youth with type 2 diabetes with metabolic syndrome (342).

Data from imaging studies have been reported in recent years. Cree-Green et al. found a higher prevalence of MASLD by liver MRI in 27 adolescents with type 2 diabetes versus 21 controls of similar BMI, pubertal stage, and habitual activity (33% vs. 24%) (343). The Surgical or Medical Treatment for Pediatric Type 2 Diabetes (ST2OMP) clinical trial, which began in 2019, was designed to evaluate the effects of bariatric surgery versus currently available medical pharmacotherapies on glycemic management and diabetes comorbidities in adolescents age 13–19 years with type 2 diabetes (344). Preliminary data evaluating ALT, liver fat by MRI, and liver stiffness by MR elastography in 56 youth with type 2 diabetes undergoing bariatric surgery indicated that MASLD assessed by proton density fat fraction (PDFF) ≥5% occurred in 89.0% of youth with type 2 diabetes, increased liver stiffness in 14.8%, and elevated ALT levels in 76.4%. Adjusted for age, BMI, and A1C, PDFF and ALT were significantly higher in males versus females and significantly lower in youth taking a GLP-1 receptor agonist versus other medication classes. Non-Hispanic White youth had the highest liver stiffness (345).

In Manitoba, Wittmeier et al. observed a prevalence of hepatic steatosis (based on spectroscopy measures) in youth with type 2 diabetes recruited from a pediatric diabetes clinic of 64% compared with 27% in overweight normoglycemic controls recruited through community advertisements (346). Furthermore, only 31% of youth with type 2 diabetes had evidence of steatosis with elevated ALT levels. Another study in Canada using surveillance data among Aboriginal youth with type 2 diabetes (n=227, mean age 15.3 years) reported a lower prevalence of 22.17%, using elevated ALT levels for diagnosis (347).

Globally, in a meta-analysis of 26 studies of youth with type 2 diabetes, including 1,053 children and adolescents (diabetes duration 0–4.6 years), Hu et al. reported an overall pooled prevalence of 33.8% for MASLD by ultrasound, MRI, or liver transaminases (348). By region, the pooled prevalence of MASLD in 11 studies in North America was 30.5% (n=2,822), a rate similar to that of Asia (32.2%), but higher than Europe (22.5%) and lower than the Middle East (55.9%) (348). This meta-analysis has caveats, including some studies using only liver transaminases, others using ultrasound, BMI not reported in some studies, and unclear methods for the definition of diabetes type; however, the MASLD prevalence in the studies using MRI was very high at 54.72% (95% CI 34.76%–73.95%, p<0.01).

In summary, preliminary data in youth indicate a high prevalence of MASLD in youth with type 2 diabetes, with likely progression to metabolic dysfunction-associated steatohepatitis (MASH) and fibrosis in a subset, despite young age. In contrast, MASLD in youth with type 1 diabetes appears more related to increasing rates of obesity within youth with type 1 diabetes, rather than type 1 diabetes per se. Large, robust studies for early detection of MASLD are needed in youth with both types of diabetes and in comparison with control groups of youth of similar BMI, race/ethnicity, and pubertal stage.

### Cardiovascular Risk Factors

The cardiovascular risk factors discussed in this section include glycemia, elevated blood pressure, dyslipidemia, and obesity. Since cardiovascular risk factors track from childhood to adulthood (349,350) and risk factors measured in youth predict adult target organ damage (351,352,353), it is important to evaluate them in youth prior to the onset of clinical complications. An adverse risk profile among youth with diabetes may magnify the already threefold excess risk for cardiovascular mortality associated with diabetes in adulthood (354). Following the discussion of risk factors, measures of subclinical CVD are reviewed, including arterial stiffness, carotid intima-media thickness (cIMT), and coronary artery calcification (CAC).

Of interest, most data suggest that cardiovascular risk factor profiles and measures of subclinical CVD are usually worse in youth with type 2 diabetes than those with type 1 diabetes. Traditional cardiovascular risk factors (hypertension, dyslipidemia) are highly prevalent in youth and young adults with type 2 diabetes, with prevalence increasing over time and cardiovascular outcomes occurring at a younger age. Data from TODAY revealed that by the end of the study (mean duration of ~4.5 years), 83% of the cohort had one or more cardiovascular risk factors (hypertension, LDL cholesterol dyslipidemia, hypertriglyceridemia, or smoking) at an average of only 24 years of age (355). In addition, the SEARCH study demonstrated in its large, diverse cohort that the number of cardiovascular risk factors did not change significantly over time in youth with type 1 diabetes, but increased significantly in participants with type 2 diabetes (356). Data from North American youth are summarized in Table 6 and briefly described below.

#### Glycemic Control

Older observational studies have established the role of intensive glycemic management in reducing the risk of CVD in both type 1 and type 2 diabetes after 20–35 years of duration (357,358,359). A report from Sweden showed a significantly reduced risk of CVD with lower A1C in adults with youth-onset type 1 diabetes and 1–35 years of duration (360). In addition, the DCCT/EDIC reported substantial reductions in coronary artery disease incidence with intensive control (359). A follow-up analysis in the DCCT/EDIC cohort established the primacy of mean updated A1C as the most significant risk factor for clinical CVD, second only to increasing age (361).

Similarly, a meta-analysis of clinical trials in adults with type 1 and type 2 diabetes found a significant effect of improved glucose management on macrovascular outcomes (362). The relative risk reduction among adults with type 1 diabetes was 62% (95% CI 44%–74%) and was largely due to a reduction of cardiac and peripheral vascular events (362). Among those with type 2 diabetes, the relative risk reduction was 19% due to reductions in stroke and peripheral vascular events (362). The effects appeared to be especially important among younger patients with a shorter duration of diabetes, suggesting that improved glycemic management in youth and young adults may have long-lasting consequences. Whether improving glycemic management in more recent years has led to a reduction in CVD in cohorts with later onset remains unclear. The Pittsburgh EDC showed no change in the cumulative incidence of coronary artery disease at 20, 25, or 30 years of duration by year of diagnosis from 1950 to 1980 (242), although it did find significant reductions in kidney disease and mortality over the same period. Taken together, these studies suggest that early initiation of strict glucose management can improve future vascular outcomes, but data in the pediatric population are lacking.

Observational studies among children and youth with diabetes generally report a constellation of related sociodemographic factors that are associated with poor glycemic control, including non-White race/ethnicity, lower socioeconomic status, lower parental educational attainment, less parental involvement in diabetes management, and impaired family dynamics (363,364,365,366,367,368,369,370,371). In SEARCH, poor glycemic management (A1C ≥9.5%) was seen with increasing age, longer diabetes duration, and in youth of race/ethnicity other than non-Hispanic White; the same patterns were true for youth with type 1 or type 2 diabetes (372). Overall, 17% of youth with type 1 diabetes had poor glycemic control, as did 27% of youth with type 2 diabetes, who were older and included a higher proportion of youth other than non-Hispanic White (372). Among youth with type 1 diabetes, poorer glycemic control was more frequently observed in those using insulin regimens other than continuous subcutaneous insulin infusion (pumps), a finding that may reflect differences in socioeconomic status and access to care (197). Higher A1C was also associated with higher concentrations of apolipoprotein B (ApoB) and smaller, more dense LDL cholesterol particle size (373), as well as elevated ACR (266), suggesting possible links early in the history of diabetes between glycemic management and future risk for both macrovascular and microvascular disease.

##### Type 1 Diabetes

Early reports of glycemic trends in the post-DCCT era came from the Joslin Diabetes Center in Boston, Massachusetts. Svoren et al. enrolled two pediatric type 1 diabetes cohorts (one in 1997 and the other in 2002) and followed them prospectively for two years. The authors reported a significantly lower A1C among the cohort enrolled in 2002 compared to the cohort enrolled in 1997 at both baseline (8.4% vs. 8.7% [68 vs. 72 mmol/mol]) and study end (8.7% vs. 9.0% [72 vs. 75 mmol/mol]), attributing the difference between groups to the increased use of multiple daily insulin injections or pumps among the second cohort (374). More extensive data from Europe during this time showed a similar trend (203,375,376). Youth with type 1 diabetes in Germany and Austria showed significant improvements in glycemic management over 15 years from 1995 to 2009 (203). The mean A1C decreased from 8.9% (74 mmol/mol) to 8.1% (65 mmol/mol), and the proportion of youth in poor management (A1C >9.0%) decreased from 39.8% to 20.6%, due largely to an increase in youth receiving higher insulin doses through multiple daily injections or insulin pumps.

More extensive data capturing a diverse population of children and youth with diabetes in the United States came from SEARCH, which reported on trends across three time periods. The study found that the adjusted mean A1C increased from 8.5% (in 2002–2007) to 8.9% (2008–2013) and 8.8% (2014–2019), with significant temporal trends by age and diabetes duration (377). In multivariable models, higher A1C was significantly associated with younger age, lower BMI, not using an insulin pump, infrequent self-monitoring of blood glucose, and lower household income (377). In addition, non-Hispanic Black and American Indian youth with type 1 diabetes had an A1C level that was 1.2% higher than non-Hispanic White youth (377), similar to earlier findings by SEARCH and others (193,370,372,378).

Interestingly, the increasing trend in A1C levels in SEARCH contrasted with the decreasing trends observed in Europe and other parts of the world. Zimmermann et al. compiled longitudinal data from multiple national and international registries in youth with type 1 diabetes (age ≤18 years) and found that between 2013 and 2022, the aggregated mean A1C decreased globally from 8.2% (66 mmol/mol) to 7.6% (60 mmol/mol) (204). However, although the proportion of participants who had achieved A1C targets of <7% (<53 mmol/mol) increased from 19.0% to 38.8%, a large proportion of youth did not meet ISPAD targets (379). Other international studies have also demonstrated improvements in glycemia, such as SWEET, which includes 22 centers from Europe, Australia, Canada, and India (mean adjusted A1C decreased from 8.4% [68 mmol/mol] to 7.9% [63 mmol/mol] between 2008–2010 and 2016–2018) (380), and the National Pediatric Diabetes Audit in England and Wales (median A1C decreased from 8.6% [70 mmol/mol] to 7.8% [62 mmol/mol] between 2011–2012 and 2019–2020 and even further to 7.6% [60 mmol/mol] by 2022–2023) (381,382).

##### Type 2 Diabetes

Early data on trends in glycemic control among youth with type 2 diabetes are limited. In SEARCH, the adjusted mean A1C decreased from 8.7% (in 2002–2007) to 8.3% (2008–2013) and increased back up to 8.6% (2014–2019), with significant temporal trends by diabetes duration but not age (377). In multivariable models, higher A1C was significantly associated with lower BMI and metformin versus insulin use (377). Despite the growing evidence establishing the rapid decline in β-cell function and the accelerated development of complications in youth-onset type 2 diabetes compared with adult-onset type 2 diabetes, glycemic management still has not improved over time (28,184,185,383,384). The adjusted mean A1C of 8.6% reported in SEARCH (diabetes duration 7 years) was similar to that of 8.4% reported in the Pediatric Diabetes Consortium Type 2 Diabetes Registry (diabetes duration ≥4 years) (385).

In TODAY (2004–2020), median A1C levels increased over the 15 years of the study (mean trial follow-up 3.9 years; remainder was observational follow-up) (185). The percentage of participants with A1C levels in the non-diabetes range (<6% [<42 mmol/mol]) decreased from 75% at baseline to 19% at 15 years, while the percentage of participants with A1C levels ≥10% (≥86 mmol/mol) started at 0% at baseline and increased to 34% by 15 years (185). An additional analysis by the TODAY study group demonstrated that higher baseline A1C and fasting glucose variability predicted youth with type 2 diabetes who went on to experience metabolic decompensation and comorbidities during 10 years of follow-up (386). In RISE (2013–2019), glycemic worsening occurred in a higher proportion of youth compared to adults (36% vs. 20%, p=0.002); independent of pharmacological intervention, β-cell dysfunction, higher A1C, and higher fasting glucose at baseline were all significant predictors of glycemic worsening in youth with type 2 diabetes (387).

Altogether, these data suggest that A1C remains unacceptably high among adolescents, and a significant proportion of these youth are not likely to see the benefits of reduced microvascular and macrovascular outcomes as they age into adulthood.

#### Elevated Blood Pressure

Hypertension in youth is typically diagnosed using age-, sex-, and height-specific blood pressure levels that are ≥95th percentile of the blood pressure distribution on repeated measurement (388). Some epidemiologic population studies, however, measure blood pressure at a single visit (389,390).

##### Type 1 Diabetes

In SEARCH, among 3,691 U.S. youth with type 1 diabetes, elevated blood pressure was present in 6.8% of those age <12 years and 5.0% of those age ≥12 years (p=0.03) (389). Only 7.4% of youth with hypertension were aware of their condition, and only 1.5% had been treated (389). The prevalence of hypertension was higher among youth of race/ethnicity other than non-Hispanic White (7.8% non-Hispanic Black, 7.6% Hispanic, 13.1% Asian and Pacific Islander, and 11.8% American Indian youth) compared with non-Hispanic White youth (5.0%), in youth with obesity with a BMI ≥95th percentile for U.S. youth (11.1%), and among those with suboptimal glycemic management (8.4%) (389). SEARCH also conducted longitudinal analyses in a sample of 1,518 participants with follow-up data; 8% of participants had prehypertension at their baseline visit, and 14.8% developed hypertension after an average of 7.1 years of follow-up (391).

Similarly, outside of North America, Australian youth with type 1 diabetes with a mean age of 18.4 years and diabetes duration of 8.7 years had a prevalence of hypertension of 19.4% (392). In the large German Diabetes Documentation System from 195 clinical centers and >27,000 youth with type 1 diabetes, the prevalence of hypertension was similar to youth without diabetes at age 0–11 years but increased slightly in 12–16-year-olds (7.4%) and was 11.0% in 17–27-year-olds (393).

##### Type 2 Diabetes

In contrast, among 410 U.S. youth with type 2 diabetes in SEARCH, 23.7% had elevated blood pressure (27% of those age <12 years and 23% ≥12 years) (389). Youth of race/ethnicity other than non-Hispanic White (27.7% non-Hispanic Black, 22.2% Hispanic, 27.0% Asian and Pacific Islander, and 21.4% American Indian youth) had higher prevalences of hypertension than non-Hispanic White youth (20.2%); youth with type 2 diabetes and overweight (17.1%) or obesity (26.5%) had higher prevalences of hypertension compared to youth with type 1 diabetes of the same age (14.8 and 11.4 years, respectively) and somewhat longer diabetes duration (18.7 and 37.4 months, respectively) (389). Among youth with type 2 diabetes and hypertension, only 31.9% were aware of their condition, and only 11.8% had been treated (389). Sellers et al. reported on 99 First Nation youth with type 2 diabetes in Manitoba (390). Elevated systolic blood pressure was observed in 13% of youth, but only 6% had elevated diastolic blood pressure. Similar to the SEARCH findings, Australian youth with type 2 diabetes and only 1.3 years of diabetes duration had a hypertension prevalence of 36% compared to 16% in youth with type 1 diabetes in the same clinic (288). In another Australian center, the prevalence of antihypertensive treatment after 11.6 years of duration for youth with type 2 diabetes was 49.3% but was only 24.6% among youth with type 1 diabetes and 14.7 years of duration (260). Given the high levels of obesity in most youth with type 2 diabetes, some of the detected hypertension may have preceded the development of diabetes.

Longitudinal studies have followed youth into adulthood to determine the long-term consequences of hypertension in youth with diabetes. In SEARCH, participants with type 2 diabetes were more likely to have prehypertension at their baseline visit (23.2% vs. 8.0%, p<0.0001) and also more likely to develop hypertension (35.6% vs. 14.8%, p<0.0001) after an average of 6.8 years of follow-up compared to youth with type 1 diabetes (mean follow-up time 7.1 years) (391). Furthermore, Koebnick et al. found a positive association between waist-to-height ratio and incident hypertension in both youth with type 1 diabetes and those with type 2 diabetes (391). During the TODAY clinical trial (n=699, onset age 10–17 years), the prevalence of hypertension at baseline was 11.6% and increased to 33.8% after ~3.9 years of follow-up (290). At baseline, non-Hispanic White youth had the highest prevalence of hypertension (17.6%), followed by non-Hispanic Black (13.7%), and Hispanic (7.9%, p<0.0039) youth; males had an 87% greater likelihood of developing hypertension than females (p=0.0002) (290). After an average of 10.2 years of observational follow-up in TODAY2, the 14-year cumulative incidence of hypertension was 59.2% (355). Males had a significantly higher likelihood of developing hypertension than females as did non-Hispanic White youth compared to Hispanic youth. Higher BMI and A1C were significantly associated with developing hypertension, as was lower insulin sensitivity (355). During the TODAY trial (mean age at randomization 14.0 years) and its observational phase (mean age at start 18.6 years), on average, 27.8% of participants reported antihypertensive medication use (36.2% males and 23.1% females) (355).

#### Dyslipidemia

Various lipid fractions are increasingly measured in youth, given that lipids track from youth into adulthood and because of the known onset of fatty streaks and early plaques in arteries of even young children (394). These lipid fractions include total cholesterol, HDL cholesterol, LDL cholesterol, very-low-density lipoprotein (VLDL) cholesterol, triglycerides, and ApoB (a marker of higher cardiovascular risk in adults), as well as the density of LDL cholesterol (with small dense LDL cholesterol conferring higher risk) and oxidized lipoprotein fractions.

Specific dyslipidemias do not appear to exist in type 1 diabetes, especially in youth, where most studies have found few differences compared with controls (395). However, among youth with type 2 diabetes, patterns typically seen in adults with type 2 diabetes (low HDL cholesterol, high triglycerides, small dense LDL cholesterol) are common (395).

##### Type 1 Diabetes

In a large clinic-based cohort in Colorado, few differences in lipid levels were observed in youth with type 1 diabetes compared to NHANES youth (396). However, higher A1C was associated with higher total cholesterol and lower HDL cholesterol. Early SEARCH data demonstrated that a significant proportion of youth with type 1 diabetes had abnormal serum lipid concentrations, especially youth age ≥10 years (397). Specifically, among 2,165 youth studied, 19% of those age ≥10 years had total cholesterol >200 mg/dL (>5.18 mmol/L), 15% had LDL cholesterol >130 mg/dL (>3.37 mmol/L), 12% had HDL cholesterol <40 mg/dL (<1.04 mmol/L), and 5% had triglycerides >200 mg/dL (>2.26 mmol/L) (397). Additional results from SEARCH have shown that lipids were significantly higher in youth with suboptimal glycemic management (373,398).

The effect of poor management was also shown in a subset of SEARCH participants in Colorado and South Carolina (the SEARCH Case-Control Study), where youth with type 1 diabetes in optimal management (A1C <7.5%) had lipid patterns similar to controls, while those with suboptimal glycemic management had elevated levels. However, ApoB and small dense LDL cholesterol were higher in youth with type 1 diabetes than in controls, even among youth in optimal glycemic management (399). Thus, even if absolute levels of total and LDL cholesterol appear similar in youth with type 1 diabetes and controls, those in suboptimal glycemic management have more atherogenic lipid profiles. Maahs et al. extended these cross-sectional observations and showed that changes in A1C levels over 2 years were significantly associated with parallel changes in lipids (400). For example, an improvement in A1C of 1% over 2 years (from 8.0% to 7.0%) lowered total cholesterol by 3.9 mg/dL (0.10 mmol/L) (400). Therefore, glycemic management and lipids are related, and better management reduces lipid levels. Factors other than higher A1C associated with dyslipidemia in youth with type 1 diabetes include greater waist-to-height ratio, male sex, and higher BMI (401,402).

More recent data from the SEARCH study in 2017 reported that among n=1,478 youth with type 1 diabetes (onset age <20 years, mean diabetes duration 8.1 years), 19% of the cohort progressed from normal to abnormal non-HDL cholesterol concentrations over an average of 7.1 years of follow-up (401). Furthermore, 7% of youth had sustained abnormal non-HDL cholesterol over time, and only 5% regressed from abnormal to normal over the 7 years (401). These estimates, although still concerning, were slightly lower than those reported a decade earlier by Maahs et al. in a retrospective clinic-based study in Colorado where the prevalence of sustained dyslipidemia (non-HDL cholesterol ≥130 mg/dL) was 27.8% over a mean follow-up time of 2.9 years in 360 youth with type 1 diabetes (402). The lower prevalence observed in the SEARCH study may be due to the exclusion of participants on lipid-lowering medications.

##### Type 2 Diabetes

Youth with type 2 diabetes have substantially more atherogenic lipid profiles than youth without diabetes and youth with type 1 diabetes of the same age. Cross-sectional work from the SEARCH study reported that among 283 youth with type 2 diabetes (age ≥10 years), 33% had total cholesterol >200 mg/dL, 24% had LDL cholesterol >130 mg/dL, 44% had HDL cholesterol <40 mg/dL, and 26% had triglycerides >200 mg/dL (397). Prevalence of high total cholesterol, high LDL cholesterol, low HDL cholesterol, and high triglycerides was significantly higher in participants with type 2 diabetes than in similarly aged youth with type 1 diabetes in the same study (n=1,680) (397). Similar to youth with type 1 diabetes, strong cross-sectional associations between A1C level and lipid levels were also reported in youth with type 2 diabetes (373,398). An elevated total cholesterol (≥200 mg/dL) was observed among 14% of youth with type 2 diabetes in optimal management (A1C <6.7% [<50 mmol/mol]) compared to 65% of youth with A1C ≥9.5% (398). This was also true for small dense LDL cholesterol and ApoB (373). Similar patterns were observed among First Nation youth with type 2 diabetes in Manitoba, with significant differences from controls for all measured lipids (390). In addition, Fortmeier-Saucier et al. found that 75% of Mexican American youth with type 2 diabetes had two or more abnormal lipid values (403).

In longitudinal analyses conducted over a 7-year follow-up period in SEARCH, 44.4% of youth with type 2 diabetes (n=212, onset age <20 years, mean diabetes duration 7.9 years) either progressed from normal to abnormal LDL over follow-up (progressed) or began and ended follow-up with an abnormal LDL (stable) (404). In addition, more than one-third (33.5%) of youth with type 2 diabetes had progression to or stable abnormal triglycerides at follow-up (404). Each 1% increase in A1C AUC (area under the curve) was associated with a 20% increased risk of abnormal LDL at follow-up and a 13% increased risk of abnormal triglycerides at follow-up. Similarly, during the TODAY clinical trial (n=699, onset age 10–17 years), the prevalence of LDL cholesterol >100 mg/dL (>2.59 mmol/L) increased from 28.1% at baseline to 34.7% at 36 months of follow-up, while the prevalence of triglycerides ≥150 mg/dL (≥1.70 mmol/L) increased from 21.0% to 23.3% (405). Improvements in HDL cholesterol were observed over time in both the SEARCH and TODAY studies (404,405). After 10.2 years of observational follow-up in TODAY, the 14-year cumulative incidence was 32.9% for LDL dyslipidemia and 37.4% for hypertriglyceridemia (355). Both elevated LDL and triglycerides were associated with higher A1C over time. A little more than half of the participants (56.1%) met targets for LDL <100 mg/dL (355). Lastly, in both SEARCH and TODAY, males had significantly higher triglyceride levels than females, as did non-Hispanic White youth compared to Hispanic and non-Hispanic Black youth (355,405,406).

#### Obesity and Insulin Resistance

Obesity and its accompanying insulin resistance play a significant role in the development of cardiovascular endpoints and likely contribute to the excess CVD risk and excess mortality in persons with diabetes. As the worldwide population of children has developed higher prevalence of overweight and obesity, so too have youth with both type 1 and type 2 diabetes.

##### Type 1 Diabetes

In Pittsburgh, data on overweight youth with type 1 diabetes onset in 1979–1989 were compared to data from 1990–1998 cohorts (407). A tripling of overweight was noted in both antibody-positive (type 1 diabetes) and antibody-negative (possible type 2 diabetes) youth. The prevalence of overweight was greatest in non-Hispanic Black youth in both time periods. Comparing the prevalence of overweight and obesity in youth with type 1 diabetes to NHANES data, SEARCH showed that the prevalence of obesity was similar among youth with and without diabetes, while the prevalence of overweight was substantially higher in all race/ethnicity groups with diabetes (20%–23%) compared to those without diabetes (14%–19%) (33). This excess adiposity also increased insulin resistance in youth with type 1 diabetes (408).

##### Type 2 Diabetes

One of the hallmarks of the presentation of type 2 diabetes in youth is obesity (409). In SEARCH in 2001–2004, 70%–90% of youth with type 2 diabetes had obesity compared with 15%–20% of the U.S. population (33). Similarly, in Canadian First Nation youth with type 2 diabetes in 1997–2002, overweight and obesity were present in 83% of the population (390). In Australian youth with type 2 diabetes, 81% had overweight or obesity compared to only 32% of youth with type 1 diabetes (288). More recently, in a meta-analysis performed by Cioana et al., the pooled prevalence of obesity from 53 studies including 8,942 youth with type 2 diabetes was 75.3%, with significantly higher rates in males than females (78.7% vs. 59.2%) (410). Prevalence estimates were highest in non-Hispanic White youth (89.9%), followed by non-Hispanic Black (84.5%), Middle Eastern (82.2%), Hispanic (81.3%), Indigenous (76.7%), and Asian (64.5%) youth (410). Data from 30 of these studies reported an obesity prevalence of 77.2% at diabetes diagnosis; data analyzed by region demonstrated that North America had the highest prevalence of obesity at 81.1%, followed by the Middle East (78.4%) and Oceania (74.0%) (410).

Hyperinsulinemic euglycemic and hyperglycemic clamps have been conducted in youth with type 2 diabetes and controls with obesity alone to assess IS and β-cell function directly (278,411). The RISE study measured β-cell function using two-stage hyperglycemic clamps and 3-hour OGTTs in 91 youth (age 10–17 years) and 267 adults (age 18–65 years) with recently diagnosed type 2 diabetes. Despite similar glucose values, youth with type 2 diabetes had much higher levels of insulin and C-peptide than comparably overweight dysglycemic adults and a 46% lower IS (412,413). Across all levels of IS, RISE youth had more responsive β-cells; the mechanisms of this finding are uncertain but could represent a fundamental difference in the natural course of β-cell dysfunction between youth and adults and may explain the rapid rate of β-cell deterioration in youth compared with adults. Additional analyses in RISE demonstrated that pubertal youth with obesity were more insulin resistant than adults with similar levels of obesity (414). In addition, the relationships between IS and CVD risk factors were similar between youth and adults, with the exception of HDL cholesterol and systolic blood pressure (414). The effects of obesity on CVD risk factors were attributable to IS in both groups (414).

### Subclinical Cardiovascular Disease

Noninvasive techniques are used to evaluate arterial structure and function well before diabetes-related vascular disease becomes irreversible. A variety of subclinical markers of early CVD have been explored in youth with diabetes, including measures of arterial stiffness, arterial thickness (e.g., cIMT), and CAC. Studies in North American youth are summarized in Table 7.

#### Arterial Stiffness

Arteriosclerosis increases PWV and augments central arterial pressure via early wave reflection (415). Measures such as PWV, the augmentation index (AIx), brachial distensibility, and pulse pressure (systolic-diastolic difference) are used to assess stiffness. Elevated pulse pressure is common in adults with youth-onset type 1 diabetes and predicts CVD (416). PWV is associated with CVD risk factors (417) and predicts mortality in type 1 and type 2 diabetes, independent of traditional risk factors and glycemia (418,419). Greater abnormalities in youth with diabetes than in youth without diabetes suggest earlier CVD onset and progression.

##### Type 1 Diabetes

A small study of 44 youth (mean age 14.6 years, duration 6.0 years) found that youth with type 1 diabetes are at risk for subclinical CVD within 10 years of diagnosis (420). In SEARCH, prevalence of arterial stiffness, defined as a mean carotid-femoral PWV >90th percentile compared to age- and sex-matched controls, was 19.4% in 1,809 youth with type 1 diabetes (mean age 17.6 years, diabetes duration 7.8 years) (421). After an average of 4.6 years of follow-up (n=949), carotid-femoral PWV and AIx worsened significantly (322). Stiffness in SEARCH co-occurred more often than expected with retinopathy and/or CAN (323).

Outside of North America, studies also reported increased stiffness in youth with type 1 diabetes (422,423,424). A meta-analysis of 21 studies found significantly higher carotid-femoral PWV and AIx in youth with type 1 diabetes (n=1,698, mean age 15.7 years, duration 7.7 years) versus healthy controls (n=1,062, mean age 16.0 years) (425). Results were consistent with a prior meta-analysis by Giannopoulou et al. (426) that pooled data from four studies. Although two of the four studies found no difference, pooled results showed significantly higher PWV in youth with type 1 diabetes (n=975, mean age 15.2 years, diabetes duration 7.1 years) versus healthy controls (n=516, mean age 16.2 years).

In SEARCH, risk factors for arterial stiffness and arterial aging included higher A1C, older age, longer duration of diabetes, obesity, hypertension, and dyslipidemia (322,427,428). In addition, females had significantly higher AIx and carotid-femoral PWV than males, while male sex was associated with lower brachial distensibility and higher femoral-foot and carotid-radial PWVs (322,421,428). Race/ethnicity other than non-Hispanic White was associated with worse outcomes across all measures (421,428). Adjustment for modifiable CVD risk factors reduced the PWV difference between non-Hispanic Black and non-Hispanic White youth by 21%, yet non-Hispanic Black youth still had significantly higher PWV (429).

##### Type 2 Diabetes

In SEARCH, prevalence of arterial stiffness in youth with type 2 diabetes was 47.4% at 7.9 years diabetes duration (n=205, mean age 22.1 years), which was 35.9% higher than in youth with type 1 diabetes (184). Over an average of 4.6 years of follow-up (n=192), arterial stiffness worsened more rapidly in youth with type 2 diabetes than in youth with type 1 diabetes, despite similar diabetes durations (322).

In TODAY, arterial stiffness was measured in 453 participants with youth-onset type 2 diabetes (mean age 20.8 years, diabetes duration 7.6 years) (430). Compared with similarly-aged lean youth (n=241) and controls with obesity (n=234), TODAY participants had worse arterial stiffness. Almost half of the TODAY cohort (49.6%) met the criterion for increased arterial stiffness defined as a mean PWV carotid-femoral >90th percentile compared to lean participants (430). The percent abnormal ranged from 21.7% to 34.6% for the other vascular measures. Over 5 years (n=304), PWV and AIx increased 14.2%–57.8% (327), with annualized change similar to adults in their mid-50s with 15–20 years of diabetes duration (431,432). Ryder et al. followed 151 youth with type 2 diabetes and matched controls (n=141 healthy weight, n=156 obesity) and found accelerated early vascular changes (433).

Risk factors in youth with type 2 diabetes include higher A1C, older age, longer duration of diabetes, higher blood pressure, greater waist circumference, dyslipidemia, and physical inactivity (322,327,430,434). Differences by sex and race/ethnicity were observed in SEARCH (322), but not in TODAY (327). In addition, in SEARCH, stiffness was linked to reduced HRV, suggesting autonomic dysfunction (328). Arterial stiffness has also been associated with abnormal cardiac structure and function, in both youth with type 1 and type 2 diabetes (435,436).

Collectively, these studies demonstrate that youth with type 1 and type 2 diabetes have greater and progressively worsening arterial stiffness than age- and sex-matched lean youth or youth with obesity, with faster progression in type 2 diabetes. Targeting CVD risk factors, such as weight, blood pressure, and lipids, as well as strict maintenance of glycemic management, may help preserve arterial health.

#### Carotid Intima Medial Thickness

cIMT, usually measured by B-mode ultrasound, is a common structural marker of arterial health. As seen in Table 7, absolute values of cIMT vary substantially between studies (e.g., 0.32–0.57 mm), with differences between cases and controls often measured in hundredths of a millimeter.

##### Type 1 Diabetes

In a small Michigan study, Singh et al. reported no differences in cIMT between youth with type 1 diabetes and controls, but less flow-mediated dilatation in cases (437). A larger California study found significantly thicker cIMT in youth with type 1 diabetes than controls, but few factor correlates (438). In SEARCH, cIMT was greater in 402 youth with type 1 diabetes versus 206 matched controls from Colorado and Ohio, with no differences at specific arterial sites; adjustment for A1C attenuated the difference (439). In a 5-year SEARCH follow-up (n=298), mean age rose from 13.3 to 19.2 years, and the proportion of participants with two or more CVD risk factors increased from 40% to 53% (440). cIMT also increased over 5-year follow-up, suggesting early vascular damage.

In Vancouver, Canada, Glackin et al. found youth with type 1 diabetes had sixfold higher odds of ambulatory blood pressure monitoring (ABPM) abnormalities than controls, which were linked to greater cIMT (441). This relationship was positively influenced by BMI (441).

Outside of North America, a meta-analysis of 20 studies in 16 countries found significantly greater cIMT in youth with type 1 diabetes (n=1,885, mean age 14.9 years, diabetes duration 6.9 years) versus healthy controls (n=1,345, mean age 14.8 years) (426). Similar to the results from the Glackin et al. study, in South Korea, 52% of youth with type 1 diabetes had ABPM abnormalities and higher cIMT than normotensive youth (442). A German study also showed that cIMT progression over 4 years was predicted by baseline BMI, A1C, and systolic blood pressure (443).

In the DCCT/EDIC, cIMT progression over the first 6 years of EDIC follow-up was lower in the former intensive therapy group than in the conventional treatment group (444). Changes in years 6–12 were similar, underscoring the importance of early intensive therapy (444,445).

Factors associated with cIMT in the SEARCH study were older age, male sex, higher BMI, LDL cholesterol, and systolic blood pressure, with the strongest associations noted with BMI and blood pressure, as well as with A1C (439,440,441,446).

##### Type 2 Diabetes

In Cincinnati, Ohio, youth with type 2 diabetes had significantly thicker cIMT across all segments than lean controls and thicker bulb/common carotid than controls with obesity without diabetes (447). Older age, male sex, higher BMI, and higher A1C were all associated with thicker cIMT (448,449). Each 1% increase in A1C or each 1-year increase in the duration of type 2 diabetes was associated with ~30% increased odds of a thicker cIMT (448). Higher diastolic blood pressure and LDL cholesterol were associated with thicker internal cIMT. Longitudinally, Ryder et al. found greater positive changes in common, bulb, and internal cIMT in 151 youth with type 2 diabetes versus healthy weight controls (n=141 healthy weight, n=156 obesity) (433).

In Manitoba, Guillemette et al. reported reduced carotid strain but no differences in cIMT between youth with type 2 diabetes and Indigenous controls without diabetes (450). In another Manitoba study, no differences in cIMT were observed between youth with type 2 diabetes with versus without albuminuria, despite similar disease duration (451). Two small studies outside of North America reported higher cIMT in youth with type 2 diabetes versus lean controls and controls with obesity, with risk factors including higher A1C, longer duration of diabetes, greater insulin resistance, higher BMI, and higher blood pressure (452,453).

Diabetes of both types commonly increases arterial wall thickness within a few years of onset and well before clinical CVD symptoms. Direct comparisons between diabetes types are limited.

#### Coronary Artery Calcification

Evaluation of the amount of calcium located in the coronary arteries measured by electron beam tomography or multislice detector CT is a well-established tool for predicting cardiovascular event risk in adults, independent of other measured risk factors. Because CAC prevalence is low in youth and rises sharply with age, few studies of young persons with short-duration diabetes have been conducted.

##### Type 1 Diabetes

In a clinic-based study of 101 young people with type 1 diabetes age 17–29 years, with a minimum of 5 years of diabetes duration, Starkman et al. found the prevalence of CAC scores >0 to be 15.1% in males and 6.3% in females (454). Smokers had a fivefold higher prevalence, but there were no significant associations with A1C, diabetes duration, BMI, or microalbuminuria, although the sample size was small (454). The Pittsburgh EDC study of the progression of CAC scores found that traditional CVD risk factors and increasing BMI were associated with increasing CAC scores, but A1C was not associated with progression (455). A follow-up study in the EDC, demonstrated that greater CAC burden was associated with clinically relevant cognitive impairment in participants with youth-onset type 1 diabetes (456).

In Denver, Colorado, the Coronary Artery Calcification in Type 1 Diabetes (CACTI) study included >500 participants with type 1 diabetes (age 20–55 years, mean duration 23 years) (457). Compared to controls, CAC prevalence was 2.1 times higher in males and 3.6 times higher in females, mirroring the excess cardiovascular risk in women with diabetes; in the youngest group (age 20–29 years), prevalence was 24% in males and 14% in females. CAC progression was strongly associated with poor glycemic control, higher BMI, and higher insulin dose (458) and, in longer follow-up, with lower HRV (459).

In the DCCT/EDIC, CAC was measured in 86% of surviving DCCT/EDIC participants 7–9 years after DCCT closeout (460). Prevalences of CAC >0 and >200 Agatston units were 31.0% and 8.5%, respectively. The intensive treatment group had lower geometric mean CAC scores and lower prevalence of CAC >0 in the primary prevention cohort, but not in the secondary prevention cohort, a difference that was largely explained by A1C levels. When both cohorts were combined, CAC >200 was significantly less prevalent in the intensive therapy group. Older age, male sex, smoking, higher albumin excretion rate, greater waist-hip ratio, hypertension, and higher DCCT A1C were independently associated with higher CAC scores up to 9 years post-trial. Together with the cIMT findings, these results demonstrate that early, intensive glucose management can slow atherosclerosis progression.

##### Type 2 Diabetes

No studies have explored CAC in youth-onset type 2 diabetes.

### Mortality

The most recent data on mortality in youth-onset diabetes come from SEARCH. The SEARCH study includes youth-onset type 1 and type 2 diabetes cases diagnosed between 2002 and 2015 from geographically defined populations across the United States, including Indian Health Service beneficiaries from American Indian populations in the southwestern United States. Data are summarized in Table 8.

#### Type 1 Diabetes

SEARCH assessed short-term mortality for youth with type 1 diabetes. Among 14,721 youth with type 1 diagnosed before age 20 years, based on a mean follow-up time from diagnosis of 8.7 years, the crude mortality rate was 103.0 per 100,000 and the standardized mortality rate (SMR) was 1.5 (95% CI 1.2–1.8) (461). The mean age at death/follow-up was 18.7 ± 5.9 years. The SMR was significantly higher compared with the underlying U.S. population for individuals age <20 years (1.7 and 2.5 for those diagnosed at ages <15 and 15–19 years, respectively) for non-Hispanic White (1.4) and Hispanic (1.8) individuals and for females (2.0) but not males. The most frequent underlying cause of death was diabetes (42.1%), with the majority having ICD-10 codes related to ketoacidosis or coma, followed by external morbidity and mortality, including accidental injury (12.8%), transport/motor vehicle accidents (12.0%), and intentional self-harm (9.8%).

#### Type 2 Diabetes

Studies of mortality among youth-onset type 2 diabetes remain uncommon. Youth with presumed type 2 diabetes in Chicago had slightly higher mortality rates after 7.8 years of follow-up (288 per 100,000 person-years) than youth with presumed type 1 diabetes (237 per 100,000 person-years) (462).

SEARCH assessed short-term mortality for youth with type 2 diabetes. Among 4,141 youth with type 2 diagnosed before age 20 years, based on a mean follow-up time from diagnosis of 7.8 years, the crude mortality rate was 161.5 per 100,000 and the SMR was 2.3 (95% CI 1.7–3.0) (461). The mean age at death/follow-up was 23.0 ± 4.7 years. The SMR was significantly higher than the underlying U.S. population for individuals age <25 years (6.9, 5.9, and 2.4 for those diagnosed at ages <15, 15–19, and 20–24 years, respectively) among all race/ethnicity groups except non-Hispanic White (1.8, 1.9, and 3.5 for non-Hispanic Black, Hispanic, and other/unknown, respectively) and among both males (2.8) and females (2.2). The SMR for youth with type 2 diabetes was significantly higher than for youth with type 1 diabetes (2.3 vs. 1.5, p<0.0001). The underlying cause of death was diabetes for 9.1% of decedents; however, the most frequent underlying cause was external morbidity and mortality, including injury (10.9%), assault (9.1%), and transport/motor vehicle accidents (7.3%), followed by cancer (10.9%) and diseases of the circulatory system (9.1%).

#### All Types of Diabetes

Saydah et al. estimated the trend in mortality rates for all types of diabetes among youth age ≤19 years in 2000–2014 in the United States (Figure 6, Table 8) (463). No statistically significant changes in diabetes death rates were observed from 2000–2002 to 2012–2014; however, disparities persisted among race/ethnicity groups, with the highest rates among non-Hispanic Black youth and the lowest rates among Hispanic youth.

### Cognitive, Mental Health, and Psychosocial Outcomes

Evidence on neuropsychiatric outcomes in youth with type 1 and type 2 diabetes remains limited. Although dementia is increasingly recognized in adults with diabetes, rigorous pediatric data on neurocognitive systems and brain function are sparse. Clinically observed comorbidities, including depression, anxiety, and suicidality, are present, and selected cohort and registry studies report associations. For a comprehensive summary of psychosocial and behavioral health in youth, including depressive disorders and symptoms, diabetes distress, anxiety disorders, eating disorders, and other mental health diagnoses, see the Diabetes in America article Psychosocial and Behavioral Health Among Youth and Adults With Diabetes (464).

## Quality of Care

Data on the quality of care in youth with diabetes are sparse. Despite the increasing data demonstrating high rates of complications in youth with diabetes, evidence to date suggests that the quality of care for this age group is relatively poor, with low rates of A1C testing and regular examinations (e.g., eye exams) (465,466), particularly in youth of race/ethnicity other than non-Hispanic White and in low-income youth (467,468). More importantly, despite the increased availability of diabetes technology and newer therapies, a high proportion of youth with type 1 and type 2 diabetes in the United States are still not meeting the recommended targets for glycemic control (A1C <7.0%), particularly in youth with longer diabetes duration (377,466).

Factors associated with not meeting recommended guidelines typically included older age, lower income (465), lack of insurance coverage, and lower education (467,469). SEARCH reported that participants with higher past A1C levels had decreased odds of meeting future screening criteria, underscoring the need for improving the delivery of care (470). Socioeconomic barriers are significant determinants of the quality of care for youth with diabetes, directly influencing technology adoption, disease management, and treatment outcomes.

Additional research on the quality and processes of care focusing on youth with diabetes is urgently needed. Further details are described in the Diabetes in America articles Quality of Care in Adults With Diabetes and Health Insurance and Diabetes (471,472).

## Conclusions and Future Directions

Diabetes is one of the most prevalent chronic diseases in childhood, yet major gaps remain in understanding the epidemiology of youth-onset diabetes and its complications. Studies to date have shown that the prevalence of youth-onset type 2 diabetes is increasing in parallel with the rising rates of obesity in North America. Moreover, youth-onset type 2 diabetes presents a more aggressive and complex phenotype than adult-onset type 2 diabetes, with earlier and more rapid development of complications, leading to increased morbidity and reduced quality of life. Youth-onset type 1 diabetes is also on the rise globally; however, its causes remain unclear. In the United States, few comprehensive population-based studies have examined diabetes by type in diverse racial and ethnic groups. Continued and expanded surveillance is essential in light of the growing public health burden. Without identification of causes and the implementation of prevention strategies, these trends are projected to worsen.

Effective prevention will require both individualized clinical care and broader public health efforts focused on mitigating early-life risk factors. Early-onset diabetes increases the duration of disease exposure, raising the risk of long-term vascular complications and cardiovascular disease. Evidence suggests that youth with type 2 diabetes may face higher complication risks than those with type 1 diabetes. However, large-scale studies are limited by the absence of standardized protocols and validated surrogate endpoints.

As more youth are diagnosed with diabetes, the demand for high-quality care and the cost of managing diabetes will escalate (473). Advancing knowledge of the multifactorial causes of childhood diabetes and its complications is critical. Doing so can improve quality of life for affected youth and lead to effective prevention. The scientific and public health challenges are substantial, but inaction will have serious long-term consequences.

## List of Abbreviations

A1C: glycated hemoglobin
AAPC: adjusted annualized percent change
ABPM: ambulatory blood pressure monitoring
ACR: albumin:creatinine ratio
ADA: American Diabetes Association
AER: albumin excretion rate
AIx: augmentation index
ALT: alanine aminotransferase
ApoB: apolipoprotein B
AST: aspartate aminotransferase
BMI: body mass index
CAC: coronary artery calcification
CAN: cardiovascular autonomic neuropathy
CAP: controlled attenuation parameter
CDC: Centers for Disease Control and Prevention
CGM: continuous glucose monitoring
CI: confidence interval
cIMT: carotid (artery) intima-media thickness
COVID-19: coronavirus disease of 2019
CT: computed tomography
CVD: cardiovascular disease
DCCT: Diabetes Control and Complications Trial
DKA: diabetic ketoacidosis
DPN: diabetic peripheral neuropathy
EDC: Epidemiology of Diabetes Complications Study
EDIC: Epidemiology of Diabetes Interventions and Complications study
eGFR: estimated glomerular filtration rate
ETDRS: Early Treatment Diabetic Retinopathy Study
GADA: glutamic acid decarboxylase autoantibody
GFR: glomerular filtration rate
GLP-1: glucagon-like peptide-1
HDL: high-density lipoprotein
HLA: human leukocyte antigen
HRV: heart rate variability
IA-2A: insulinoma associated-2 autoantibodies
IAA: insulin autoantibody
ICD-9/10: International Classification of Diseases, Ninth/Tenth Revision
IDF: International Diabetes Federation
IRR: incidence rate ratio
IS: insulin sensitivity
ISPAD: International Society for Pediatric and Adolescent Diabetes
LDL: low-density lipoprotein
MASLD: metabolic dysfunction-associated steatotic liver disease
MNSI: Michigan Neuropathy Screening Instrument
MODY: maturity-onset diabetes of the young
MRI: magnetic resonance imaging
NHANES: National Health and Nutrition Examination Survey
NHIS: National Health Interview Survey
NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases
OGTT: oral glucose tolerance test
OR: odds ratio
PWV: pulse wave velocity
RISE: Restoring Insulin Secretion study
SEARCH: SEARCH for Diabetes in Youth study
SMR: standardized mortality ratio
TEDDY: The Environmental Determinants of Diabetes in the Young study
TODAY: Treatment Options for type 2 Diabetes in Adolescents and Youth
TODAY2: long-term observational follow-up of the TODAY trial
WDRS: Wisconsin Diabetes Registry Study
WESDR: Wisconsin Epidemiologic Study of Diabetic Retinopathy

## Conversions

A1C: (% x 10.93) - 23.50 = mmol/mol

Glucose: mg/dL x 0.0555 = mmol/L

HDL/LDL cholesterol: mg/dL x 0.0259 = mmol/L

Triglycerides: mg/dL x 0.0113 = mmol/L

## Article History

Received in final form on August 15, 2025.

## Acknowledgment

This is an update of: Dabelea D, Hamman RF, Knowler WC. Diabetes in Youth. Chapter 15 in Diabetes in America, 3rd edition. Cowie CC, Casagrande SS, Menke A, Cissell MA, Eberhardt MS, Meigs JB, Gregg EW, Knowler WC, Barrett-Connor E, Becker DJ, Brancati FL, Boyko EJ, Herman WH, Howard BV, Narayan KMV, Rewers M, Fradkin JE, Eds. Bethesda, MD, National Institute of Health, NIH Pub No. 17-1468, 2018, p. 15.1–15.54

## References

1 Imperatore G, Boyle JP, Thompson TJ, et al. Projections of type 1 and type 2 diabetes burden in the U.S. population aged <20 years through 2050: dynamic modeling of incidence, mortality, and population growth. Diabetes Care. 2012;35(12):2515-2520. doi:10.2337/dc12-0669 23173134
2 Dabelea D, Hamman RF, Knowler WC. Diabetes in youth. In: Cowie CC, Casagrande SS, Menke A, et al, eds. Diabetes in America. 3rd ed. National Institute of Diabetes and Digestive and Kidney Diseases; 2018; 15.1-15.54:chap 15. https://www.ncbi.nlm.nih.gov/books/NBK567997/
3 Hirsch IB, Pihoker C, Roberts A, Zenno A, Le P. Medication use and self-care practices in persons with diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2024. https://www.ncbi.nlm.nih.gov/books/NBK607283/
4 Salguero MV, Arosemena M, Pollin T, et al. Monogenic forms of diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597414/
5 American Diabetes Association Professional Practice Committee. 2. Diagnosis and Classification of Diabetes: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S27-S49. doi:10.2337/dc25-S002 39651986
6 Barker JM, Barriga KJ, Yu L, et al. Prediction of autoantibody positivity and progression to type 1 diabetes: Diabetes Autoimmunity Study in the Young (DAISY). J Clin Endocrinol Metab. 2004;89(8):3896-3902. doi:10.1210/jc.2003-031887 15292324
7 Wasserfall CH, Atkinson MA. Autoantibody markers for the diagnosis and prediction of type 1 diabetes. Autoimmun Rev. 2006;5(6):424-428. doi:10.1016/j.autrev.2005.12.002 16890898
8 Yu L, Boulware DC, Beam CA, et al. Zinc transporter-8 autoantibodies improve prediction of type 1 diabetes in relatives positive for the standard biochemical autoantibodies. Diabetes Care. 2012;35(6):1213-1218. doi:10.2337/dc11-2081 22446173
9 Pihoker C, Gilliam LK, Hampe CS, Lernmark Å. Autoantibodies in diabetes. Diabetes. 2005;54(Suppl 2):S52-S61. doi:10.2337/diabetes.54.suppl_2.s52 16306341
10 Graham J, Hagopian WA, Kockum I, et al. Genetic effects on age-dependent onset and islet cell autoantibody markers in type 1 diabetes. Diabetes. 2002;51(5):1346-1355. doi:10.2337/diabetes.51.5.1346 11978629
11 Vermeulen I, Weets I, Asanghanwa M, et al. Contribution of antibodies against IA-2β and zinc transporter 8 to classification of diabetes diagnosed under 40 years of age. Diabetes Care. 2011;34(8):1760-1765. doi:10.2337/dc10-2268 21715527
12 Insel RA, Dunne JL, Atkinson MA, et al. Staging presymptomatic type 1 diabetes: a scientific statement of JDRF, the Endocrine Society, and the American Diabetes Association. Diabetes Care. 2015;38(10):1964-1974. doi:10.2337/dc15-1419 26404926
13 Haller MJ, Bell KJ, Besser REJ, et al. ISPAD Clinical Practice Consensus Guidelines 2024: Screening, Staging, and Strategies to Preserve Beta-Cell Function in Children and Adolescents with Type 1 Diabetes. Horm Res Paediatr. 2024;97(6):529-545. doi:10.1159/000543035 39662065
14 Sosenko JM, Palmer JP, Rafkin-Mervis L, et al. Incident dysglycemia and progression to type 1 diabetes among participants in the Diabetes Prevention Trial-Type 1. Diabetes Care. 2009;32(9):1603-1607. doi:10.2337/dc08-2140 19487644
15 Krischer JP, Type 1 Diabetes TrialNet Study Group. The use of intermediate endpoints in the design of type 1 diabetes prevention trials. Diabetologia. 2013;56(9):1919-1924. doi:10.1007/s00125-013-2960-7 23744306
16 Hannon TS, Rao G, Arslanian SA. Childhood obesity and type 2 diabetes mellitus. Pediatrics. 2005;116(2):473-480. doi:10.1542/peds.2004-2536 16061606
17 Bobo N, Evert A, Gallivan J, et al. An update on type 2 diabetes in youth from the National Diabetes Education Program. Pediatrics. 2004;114(1):259-263. doi:10.1542/peds.114.1.259 15231940
18 Linder B, Imperatore G. Research updates on type 2 diabetes children. NASN Sch Nurse. 2013;28(3):138-140. doi:10.1177/1942602X13479402 23767228
19 Savage PJ, Bennett PH, Senter RG, Miller M. High prevalence of diabetes in young Pima Indians: evidence of phenotypic variation in a genetically isolated population. Diabetes. 1979;28(10):937-942. doi:10.2337/diab.28.10.937 478185
20 Dabelea D, Hanson RL, Bennett PH, Roumain J, Knowler WC, Pettitt DJ. Increasing prevalence of type II diabetes in American Indian children. Diabetologia. 1998;41(8):904-910. doi:10.1007/s001250051006 9726592
21 Dean H. NIDDM-Y in First Nation children in Canada. Clin Pediatr (Phila). 1998;37(2):89-96. doi:10.1177/000992289803700205 9492116
22 Scott CR, Smith JM, Cradock MM, Pihoker C. Characteristics of youth-onset noninsulin-dependent diabetes mellitus and insulin-dependent diabetes mellitus at diagnosis. Pediatrics. 1997;100(1):84-91. doi:10.1542/peds.100.1.84 9200365
23 Neufeld ND, Raffel LJ, Landon C, Chen YD, Vadheim CM. Early presentation of type 2 diabetes in Mexican-American youth. Diabetes Care. 1998;21(1):80-86. doi:10.2337/diacare.21.1.80 9538974
24 Macaluso CJ, Bauer UE, Deeb LC, et al. Type 2 diabetes mellitus among Florida children and adolescents, 1994 through 1998. Public Health Rep. 2002;117(4):373-379. doi:10.1093/phr/117.4.373 12477919
25 Kelsey MM, Pyle L, Hilkin A, et al. The impact of obesity on insulin sensitivity and secretion during pubertal progression: a longitudinal study. J Clin Endocrinol Metab. 2020;105(5):e2061-e2068. doi:10.1210/clinem/dgaa043 31996919
26 Kelsey MM, Hilkin A, Pyle L, et al. Two-year treatment with metformin during puberty does not preserve β-cell function in youth with obesity. J Clin Endocrinol Metab. 2021;106(7):e2622-e2632. doi:10.1210/clinem/dgab170 33728428
27 Bacha F, Hannon TS, Tosur M, et al. Pathophysiology and treatment of prediabetes and type 2 diabetes in youth. Diabetes Care. 2024;47(12):2038-2049. doi:10.2337/dci24-0029 39250166
28 RISE Consortium. Lack of durable improvements in β-cell function following withdrawal of pharmacological interventions in adults with impaired glucose tolerance or recently diagnosed type 2 diabetes. Diabetes Care. 2019;42(9):1742-1751. doi:10.2337/dc19-0556 31178434
29 Saad R, Gungor N, Arslanian S. Progression from normal glucose tolerance to type 2 diabetes in a young girl: longitudinal changes in insulin sensitivity and secretion assessed by the clamp technique and surrogate estimates. Pediatr Diabetes. 2005;6(2):95-99. doi:10.1111/j.1399-543X.2005.00097.x 15963037
30 Bacha F, Pyle L, Nadeau K, et al. Determinants of glycemic control in youth with type 2 diabetes at randomization in the TODAY study. Pediatr Diabetes. 2012;13(5):376-383. doi:10.1111/j.1399-5448.2011.00841.x 22332798
31 Spurr S, Bally J, Hill P, Gray K, Newman P, Hutton A. Exploring the prevalence of undiagnosed prediabetes, type 2 diabetes mellitus, and risk factors in adolescents: a systematic review. J Pediatr Nurs. 2020;50:94-104. doi:10.1016/j.pedn.2019.09.025 31786470
32 Selvin E, Wang D, Lee AK, Bergenstal RM, Coresh J. Identifying trends in undiagnosed diabetes in U.S. adults by using a confirmatory definition: a cross-sectional study. Ann Intern Med. 2017;167(11):769-776. doi:10.7326/M17-1272 29059691
33 Liu LL, Lawrence JM, Davis C, et al. Prevalence of overweight and obesity in youth with diabetes in USA: the SEARCH for Diabetes in Youth study. Pediatr Diabetes. 2010;11(1):4-11. doi:10.1111/j.1399-5448.2009.00519.x 19473302
34 Perng W, Conway R, Mayer-Davis E, Dabelea D. Youth-onset type 2 diabetes: the epidemiology of an awakening epidemic. Diabetes Care. 2023;46(3):490-499. doi:10.2337/dci22-0046 36812420
35 Minges KE, Whittemore R, Weinzimer SA, Irwin ML, Redeker NS, Grey M. Correlates of overweight and obesity in 5529 adolescents with type 1 diabetes: the T1D Exchange Clinic Registry. Diabetes Res Clin Pract. 2017;126:68-78. doi:10.1016/j.diabres.2017.01.012 28214669
36 Maffeis C, Birkebaek NH, Konstantinova M, et al. Prevalence of underweight, overweight, and obesity in children and adolescents with type 1 diabetes: data from the international SWEET registry. Pediatr Diabetes. 2018;19(7):1211-1220. doi:10.1111/pedi.12730 30033651
37 Fröhlich-Reiterer EE, Rosenbauer J, Bechtold-Dalla Pozza S, et al. Predictors of increasing BMI during the course of diabetes in children and adolescents with type 1 diabetes: data from the German/Austrian DPV multicentre survey. Arch Dis Child. 2014;99(8):738-743. doi:10.1136/archdischild-2013-304237 24812301
38 Dahlquist G, Blom L, Tuvemo T, Nyström L, Sandström A, Wall S. The Swedish Childhood Diabetes Study—results from a nine year case register and a one year case-referent study indicating that type 1 (insulin-dependent) diabetes mellitus is associated with both type 2 (non-insulin-dependent) diabetes mellitus and autoimmune disorders. Diabetologia. 1989;32(1):2-6. doi:10.1007/BF00265396 2707516
39 Dabelea D, Rewers A, Stafford JM, et al. Trends in the prevalence of ketoacidosis at diabetes diagnosis: the SEARCH for Diabetes in Youth study. Pediatrics. 2014;133(4):e938-e945. doi:10.1542/peds.2013-2795 24685959
40 Rewers A, Klingensmith G, Davis C, et al. Presence of diabetic ketoacidosis at diagnosis of diabetes mellitus in youth: the Search for Diabetes in Youth study. Pediatrics. 2008;121(5):e1258-e1266. doi:10.1542/peds.2007-1105 18450868
41 Pinhas-Hamiel O, Dolan LM, Zeitler PS. Diabetic ketoacidosis among obese African-American adolescents with NIDDM. Diabetes Care. 1997;20(4):484-486. doi:10.2337/diacare.20.4.484 9096965
42 Sellers EA, Dean HJ. Diabetic ketoacidosis: a complication of type 2 diabetes in Canadian aboriginal youth. Diabetes Care. 2000;23(8):1202-1204. doi:10.2337/diacare.23.8.1202 10937527
43 Umpierrez GE, Casals MM, Gebhart SP, Mixon PS, Clark WS, Phillips LS. Diabetic ketoacidosis in obese African-Americans. Diabetes. 1995;44(7):790-795. doi:10.2337/diab.44.7.790 7789647
44 Hathout EH, Thomas W, El-Shahawy M, Nahab F, Mace JW. Diabetic autoimmune markers in children and adolescents with type 2 diabetes. Pediatrics. 2001;107(6):E102. doi:10.1542/peds.107.6.e102 11389300
45 Libman IM, Becker DJ. Coexistence of type 1 and type 2 diabetes mellitus: “double” diabetes? Pediatr Diabetes. 2003;4(2):110-113. doi:10.1034/j.1399-5448.2003.00012.x 14655267
46 Dabelea D, Pihoker C, Talton JW, et al. Etiological approach to characterization of diabetes type: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2011;34(7):1628-1633. doi:10.2337/dc10-2324 21636800
47 Dabelea D, D’Agostino RB, Jr., Mason CC, et al. Development, validation and use of an insulin sensitivity score in youths with diabetes: the SEARCH for Diabetes in Youth study. Diabetologia. 2011;54(1):78-86. doi:10.1007/s00125-010-1911-9 20886205
48 Oram RA, Sharp SA, Pihoker C, et al. Utility of diabetes type-specific genetic risk scores for the classification of diabetes type among multiethnic youth. Diabetes Care. 2022;45(5):1124-1131. doi:10.2337/dc20-2872 35312757
49 Hamman RF, Bell RA, Dabelea D, et al. The SEARCH for Diabetes in Youth study: rationale, findings, and future directions. Diabetes Care. 2014;37(12):3336-3344. doi:10.2337/dc14-0574 25414389
50 Crume TL, Hamman RF, Isom S, et al. The accuracy of provider diagnosed diabetes type in youth compared to an etiologic criteria in the SEARCH for Diabetes in Youth Study. Pediatr Diabetes. 2020;21(8):1403-1411. doi:10.1111/pedi.13126 32981196
51 Bak JCG, Serné EH, Kramer MHH, Nieuwdorp M, Verheugt CL. National diabetes registries: do they make a difference? Acta Diabetol. 2021;58(3):267-278. doi:10.1007/s00592-020-01576-8 32770407
52 Gesuita R, Eckert AJ, Besançon S, et al. Frequency and clinical characteristics of children and young people with type 2 diabetes at diagnosis from five world regions between 2012 and 2021: data from the SWEET Registry. Diabetologia. 2025;68(1):82-93. doi:10.1007/s00125-024-06283-5 39503771
53 Patterson CC, Harjutsalo V, Rosenbauer J, et al. Trends and cyclical variation in the incidence of childhood type 1 diabetes in 26 European centres in the 25 year period 1989–2013: a multicentre prospective registration study. Diabetologia. 2019;62(3):408-417. doi:10.1007/s00125-018-4763-3 30483858
54 Wagenknecht LE, Lawrence JM, Isom S, et al. Trends in incidence of youth-onset type 1 and type 2 diabetes in the USA, 2002–18: results from the population-based SEARCH for Diabetes in Youth study. Lancet Diabetes Endocrinol. 2023;11(4):242-250. doi:10.1016/S2213-8587(23)00025-6 36868256
55 Hirsch AG, Conderino S, Crume TL, et al. Using electronic health records to enhance surveillance of diabetes in children, adolescents and young adults: a study protocol for the DiCAYA Network. BMJ Open. 2024;14(1):e073791. doi:10.1136/bmjopen-2023-073791 38233060
56 HigherGov. Comprehensive Analysis, Surveillance, and Statistics Initiative for Diabetes in the Young (CASSIDY). RFA-DP-25-043. 2024. Accessed October 28, 2025. https://www.highergov.com/grant-opportunity/comprehensive-analysis-surveillance-and-statistics-initiative-for-diabetes-in-355034/
57 Rewers M, Norris J, Dabelea D. Epidemiology of type 1 diabetes mellitus. Adv Exp Med Biol. 2004;552:219-246.15622966
58 Lipman TH, Ratcliffe SJ, Cooper R, Levitt Katz LE. Population-based survey of the prevalence of type 1 and type 2 diabetes in school children in Philadelphia. J Diabetes. 2013;5(4):456-461. doi:10.1111/1753-0407.12039 23480262
59 Demmer RT, Zuk AM, Rosenbaum M, Desvarieux M. Prevalence of diagnosed and undiagnosed type 2 diabetes mellitus among US adolescents: results from the continuous NHANES, 1999–2010. Am J Epidemiol. 2013;178(7):1106-1113. doi:10.1093/aje/kwt088 23887044
60 Fang M, Wang D, Selvin E. Prevalence of type 1 diabetes among US children and adults by age, sex, race, and ethnicity. JAMA. 2024;331(16):1411-1413. doi:10.1001/jama.2024.2103 38573653
61 Fox DA, Islam N, Sutherland J, Reimer K, Amed S. Type 1 diabetes incidence and prevalence trends in a cohort of Canadian children and youth. Pediatr Diabetes. 2018;19(3):501-505. doi:10.1111/pedi.12566 28857360
62 Lawrence JM, Divers J, Isom S, et al. Trends in prevalence of type 1 and type 2 diabetes in children and adolescents in the US, 2001–2017. JAMA. 2021;326(8):717-727. doi:10.1001/jama.2021.11165 34427600
63 Chen Y, Wang T, Liu X, Shankar RR. Prevalence of type 1 and type 2 diabetes among US pediatric population in the MarketScan Multi-State Database, 2002 to 2016. Pediatr Diabetes. 2019;20(5):523-529. doi:10.1111/pedi.12842 30861241
64 Li L, Jick S, Breitenstein S, Michel A. Prevalence of diabetes and diabetic nephropathy in a large U.S. commercially insured pediatric population, 2002–2013. Diabetes Care. 2016;39(2):278-284. doi:10.2337/dc15-1710 26681728
65 Menke A, Orchard TJ, Imperatore G, Bullard KM, Mayer-Davis E, Cowie CC. The prevalence of type 1 diabetes in the United States. Epidemiology. 2013;24(5):773-774. doi:10.1097/EDE.0b013e31829ef01a 23903880
66 Onge ES, Miller SA, Motycka C, DeBerry A. A review of the treatment of type 2 diabetes in children. J Pediatr Pharmacol Ther. 2015;20(1):4-16. doi:10.5863/1551-6776-20.1.4 25859165
67 Casagrande SS, Lessem SE, Orchard TJ, et al. Comparison of several survey-based algorithms to ascertain type 1 diabetes among US adults with self-reported diabetes. BMJ Open Diabetes Res Care. 2020;8(2):e001917. doi:10.1136/bmjdrc-2020-001917 33298431
68 Dabelea D, Mayer-Davis EJ, Saydah S, et al. Prevalence of type 1 and type 2 diabetes among children and adolescents from 2001 to 2009. JAMA. 2014;311(17):1778-1786. doi:10.1001/jama.2014.3201 24794371
69 Ogle GD, James S, Dabelea D, et al. Global estimates of incidence of type 1 diabetes in children and adolescents: results from the International Diabetes Federation Atlas, 10th edition. Diabetes Res Clin Pract. 2022;183:109083. doi:10.1016/j.diabres.2021.109083
70 Imagawa A, Hanafusa T, Miyagawa J, Matsuzawa Y. A novel subtype of type 1 diabetes mellitus characterized by a rapid onset and an absence of diabetes-related antibodies. Osaka IDDM Study Group. N Engl J Med. 2000;342(5):301-307. doi:10.1056/NEJM200002033420501 10655528
71 Nesti MM, Goldbaum M. Infectious diseases and daycare and preschool education. J Pediatr (Rio J). 2007;83(4):299-312. doi:10.2223/JPED.1649 17632670
72 Farooq MA, Parkinson KN, Adamson AJ, et al. Timing of the decline in physical activity in childhood and adolescence: Gateshead Millennium Cohort Study. Br J Sports Med. 2018;52(15):1002-1006. doi:10.1136/bjsports-2016-096933 28288966
73 Peltonen EJ, Veijola R, Ilonen J, et al. What is the role of puberty in the development of islet autoimmunity and progression to type 1 diabetes? Eur J Epidemiol. 2023;38(6):689-697. doi:10.1007/s10654-023-01002-7 37079135
74 Rogers MAM, Kim C, Banerjee T, Lee JM. Fluctuations in the incidence of type 1 diabetes in the United States from 2001 to 2015: a longitudinal study. BMC Med. 2017;15(1):199. doi:10.1186/s12916-017-0958-6 29115947
75 Rewers M, LaPorte RE, Walczak M, Dmochowski K, Bogaczynska E. Apparent epidemic of insulin-dependent diabetes mellitus in Midwestern Poland. Diabetes. 1987;36(1):106-113. doi:10.2337/diab.36.1.106 3792661
76 Nyström L, Dahlquist G, Rewers M, Wall S. The Swedish Childhood Diabetes Study. An analysis of the temporal variation in diabetes incidence 1978–1987. Int J Epidemiol. 1990;19(1):141-146. doi:10.1093/ije/19.1.141 2351509
77 Tuomilehto J, Rewers M, Reunanen A, et al. Increasing trend in type 1 (insulin-dependent) diabetes mellitus in childhood in Finland. Analysis of age, calendar time and birth cohort effects during 1965 to 1984. Diabetologia. 1991;34(4):282-287. doi:10.1007/BF00405089 2065863
78 Tuomilehto J, Virtala E, Karvonen M, et al. Increase in incidence of insulin-dependent diabetes mellitus among children in Finland. Int J Epidemiol. 1995;24(5):984-992. doi:10.1093/ije/24.5.984 8557457
79 Dokheel TM. An epidemic of childhood diabetes in the United States? Evidence from Allegheny County, Pennsylvania. Pittsburgh Diabetes Epidemiology Research Group. Diabetes Care. 1993;16(12):1606-1611. doi:10.2337/diacare.16.12.1606 7818619
80 Bruno G, Merletti F, De Salvia A, Lezo A, Arcari R, Pagano G. Comparison of incidence of insulin-dependent diabetes mellitus in children and young adults in the Province of Turin, Italy, 1984–91. Piedmont Study Group for Diabetes Epidemiology. Diabet Med. 1997;14(11):964-969. doi:10.1002/(SICI)1096-9136(199711)14:11<964::AID-DIA493>3.0.CO;2-P 9400921
81 LaPorte RE, Fishbein HA, Drash AL, et al. The Pittsburgh Insulin-Dependent Diabetes Mellitus (IDDM) registry. The incidence of insulin-dependent diabetes mellitus in Allegheny County, Pennsylvania (1965–1976). Diabetes. 1981;30(4):279-284. doi:10.2337/diab.30.4.279 7202862
82 Kostraba JN, Gay EC, Cai Y, et al. Incidence of insulin-dependent diabetes mellitus in Colorado. Epidemiology. 1992;3(3):232-238. doi:10.1097/00001648-199205000-00008 1591322
83 Padaiga Z, Tuomilehto J, Karvonen M, et al. Incidence trends in childhood onset IDDM in four countries around the Baltic Sea during 1983–1992. Diabetologia. 1997;40(2):187-192. doi:10.1007/s001250050661 9049479
84 Gregory GA, Robinson TIG, Linklater SE, et al. Global incidence, prevalence, and mortality of type 1 diabetes in 2021 with projection to 2040: a modelling study. Lancet Diabetes Endocrinol. 2022;10(10):741-760. doi:10.1016/S2213-8587(22)00218-2 36113507
85 Mefford MT, Wei R, Lustigova E, Martin JP, Reynolds K. Incidence of diabetes among youth before and during the COVID-19 pandemic. JAMA Netw Open. 2023;6(9):e2334953. doi:10.1001/jamanetworkopen.2023.34953 37733344
86 Gottesman BL, Yu J, Tanaka C, Longhurst CA, Kim JJ. Incidence of new-onset type 1 diabetes among US children during the COVID-19 global pandemic. JAMA Pediatr. 2022;176(4):414-415. doi:10.1001/jamapediatrics.2021.5801 35072727
87 McIntyre T, Sarah S, Benjamin R, Balikcioglu PG. Disrupted pediatric diabetes trends in the second year of the COVID-19 pandemic. J Endocr Soc. 2023;7(8):bvad092. doi:10.1210/jendso/bvad092 37457848
88 Guo Y, Bian J, Chen A, et al. Incidence trends of new-onset diabetes in children and adolescents before and during the COVID-19 pandemic: findings from Florida. Diabetes. 2022;71(12):2702-2706. doi:10.2337/db22-0549 36094294
89 Dabelea D, Pettitt DJ, Jones KL, Arslanian SA. Type 2 diabetes mellitus in minority children and adolescents. An emerging problem. Endocrinol Metab Clin North Am. 1999;28(4):709-729, viii. doi:10.1016/s0889-8529(05)70098-0
90 Kitagawa T, Mano T, Fujita H. The epidemiology of childhood diabetes mellitus in Tokyo metropolitan area. Tohoku J Exp Med. 1983;141 Suppl:171-179. doi:10.1620/tjem.141.suppl_171 6680483
91 Nadeau KJ, Mayer-Davis EJ, Gubitosi-Klug R, et al. Youth-onset type 2 diabetes: what we’ve learned from key youth-onset type 2 diabetes studies, what we still don’t know, and why it is important. Diabetes Care. 2025;48(7):1136-1149. doi:10.2337/dc25-0001 40272281
92 Moore KR, Harwell TS, McDowall JM, Helgerson SD, Gohdes D. Three-year prevalence and incidence of diabetes among American Indian youth in Montana and Wyoming, 1999 to 2001. J Pediatr. 2003;143(3):368-371. doi:10.1067/S0022-3476(03)00295-6 14517522
93 Lee ET, Begum M, Wang W, et al. Type 2 diabetes and impaired fasting glucose in American Indians aged 5–40 years: the Cherokee Diabetes Study. Ann Epidemiol. 2004;14(9):696-704. doi:10.1016/j.annepidem.2003.10.013 15380801
94 Amed S, Islam N, Sutherland J, Reimer K. Incidence and prevalence trends of youth-onset type 2 diabetes in a cohort of Canadian youth: 2002–2013. Pediatr Diabetes. 2018;19(4):630-636. doi:10.1111/pedi.12631 29280255
95 Sellers EAC, McLeod L, Prior HJ, Dragan R, Wicklow BA, Ruth C. Incidence and prevalence of type 2 diabetes in Manitoba children 2009–10 to 2017–18: First Nation versus all other Manitobans. Diabetes Res Clin Pract. 2024;208:111097. doi:10.1016/j.diabres.2024.111097 38244781
96 Writing Group for the SEARCH for Diabetes in Youth Study Group, Dabelea D, Bell RA, et al. Incidence of diabetes in youth in the United States. JAMA. 2007;297(24):2716-2724. doi:10.1001/jama.297.24.2716 17595272
97 Harries LW, Sloman MJ, Sellers EA, Hattersley AT, Ellard S. Diabetes susceptibility in the Canadian Oji-Cree population is moderated by abnormal mRNA processing of HNF1A G319S transcripts. Diabetes. 2008;57(7):1978-1982. doi:10.2337/db07-1663 18586913
98 Nadeau KJ, Anderson BJ, Berg EG, et al. Youth-Onset Type 2 Diabetes Consensus Report: Current Status, Challenges, and Priorities. Diabetes Care. 2016;39(9):1635-1642. doi:10.2337/dc16-1066 27486237
99 Schober E, Holl RW, Grabert M, et al. Diabetes mellitus type 2 in childhood and adolescence in Germany and parts of Austria. Eur J Pediatr. 2005;164(11):705-707. doi:10.1007/s00431-005-1709-9 16012857
100 Ortega-Rodriguez E, Levy-Marchal C, Tubiana N, Czernichow P, Polak M. Emergence of type 2 diabetes in an hospital based cohort of children with diabetes mellitus. Diabetes Metab. 2001;27(5 Pt 1):574-578.11694856
101 Feltbower RG, McKinney PA, Campbell FM, Stephenson CR, Bodansky HJ. Type 2 and other forms of diabetes in 0–30 year olds: a hospital based study in Leeds, UK. Arch Dis Child. 2003;88(8):676-679. doi:10.1136/adc.88.8.676 12876160
102 Pociot F, McDermott MF. Genetics of type 1 diabetes mellitus. Genes Immun. 2002;3(5):235-249. doi:10.1038/sj.gene.6363875 12140742
103 Redondo MJ, Onengut-Gumuscu S, Gaulton KJ. Genetics of type 1 diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597411/
104 Stene LC, Norris JM, Rewers MJ. Risk factors for type 1 diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597412/
105 Hyöty H, Taylor KW. The role of viruses in human diabetes. Diabetologia. 2002;45(10):1353-1361. doi:10.1007/s00125-002-0852-3 12378375
106 Dahlquist GG. Viruses and other perinatal exposures as initiating events for β-cell destruction. Ann Med. 1997;29(5):413-417. doi:10.3109/07853899708999371 9453289
107 Vehik K, Lynch KF, Wong MC, et al. Prospective virome analyses in young children at increased genetic risk for type 1 diabetes. Nat Med. 2019;25(12):1865-1872. doi:10.1038/s41591-019-0667-0 31792456
108 Sioofy-Khojine AB, Lehtonen J, Nurminen N, et al. Coxsackievirus B1 infections are associated with the initiation of insulin-driven autoimmunity that progresses to type 1 diabetes. Diabetologia. 2018;61(5):1193-1202. doi:10.1007/s00125-018-4561-y 29404673
109 Cinek O, Stene LC, Kramna L, et al. Enterovirus RNA in longitudinal blood samples and risk of islet autoimmunity in children with a high genetic risk of type 1 diabetes: the MIDIA study. Diabetologia. 2014;57(10):2193-2200. doi:10.1007/s00125-014-3327-4 25047648
110 Dunne JL, Richardson SJ, Atkinson MA, et al. Rationale for enteroviral vaccination and antiviral therapies in human type 1 diabetes. Diabetologia. 2019;62(5):744-753. doi:10.1007/s00125-019-4811-7 30675626
111 Bach JF. The effect of infections on susceptibility to autoimmune and allergic diseases. N Engl J Med. 2002;347(12):911-920. doi:10.1056/NEJMra020100 12239261
112 Gale EAM. A missing link in the hygiene hypothesis? Diabetologia. 2002;45(4):588-594. doi:10.1007/s00125-002-0801-1 12032638
113 TRIGR Study Group. Study design of the Trial to Reduce IDDM in the Genetically at Risk (TRIGR). Pediatr Diabetes. 2007;8(3):117-137. doi:10.1111/j.1399-5448.2007.00239.x 17550422
114 Knip M, Virtanen SM, Becker D, et al. Early feeding and risk of type 1 diabetes: experiences from the Trial to Reduce Insulin-dependent diabetes mellitus in the Genetically at Risk (TRIGR). Am J Clin Nutr. 2011;94(6 Suppl):1814S-1820S. doi:10.3945/ajcn.110.000711 21653795
115 Knip M, Åkerblom HK, Becker D, et al. Hydrolyzed infant formula and early β-cell autoimmunity: a randomized clinical trial. JAMA. 2014;311(22):2279-2287. doi:10.1001/jama.2014.5610 24915259
116 Hummel S, Beyerlein A, Tamura R, et al. First infant formula type and risk of islet autoimmunity in The Environmental Determinants of Diabetes in the Young (TEDDY) Study. Diabetes Care. 2017;40(3):398-404. doi:10.2337/dc16-1624 28096222
117 Norris JM, Barriga K, Klingensmith G, et al. Timing of initial cereal exposure in infancy and risk of islet autoimmunity. JAMA. 2003;290(13):1713-1720. doi:10.1001/jama.290.13.1713 14519705
118 Ziegler AG, Schmid S, Huber D, Hummel M, Bonifacio E. Early infant feeding and risk of developing type 1 diabetes-associated autoantibodies. JAMA. 2003;290(13):1721-1728. doi:10.1001/jama.290.13.1721 14519706
119 Uusitalo U, Liu X, Yang J, et al. Association of early exposure of probiotics and islet autoimmunity in the TEDDY Study. JAMA Pediatr. 2016;170(1):20-28. doi:10.1001/jamapediatrics.2015.2757 26552054
120 Mishra SP, Wang S, Nagpal R, et al. Probiotics and prebiotics for the amelioration of type 1 diabetes: present and future perspectives. Microorganisms. 2019;7(3):67. doi:10.3390/microorganisms7030067 30832381
121 Weets I, De Leeuw IH, Du Caju MV, et al. The incidence of type 1 diabetes in the age group 0–39 years has not increased in Antwerp (Belgium) between 1989 and 2000: evidence for earlier disease manifestation. Diabetes Care. 2002;25(5):840-846. doi:10.2337/diacare.25.5.840 11978678
122 Karvonen M, Pitkäniemi J, Tuomilehto J. The onset age of type 1 diabetes in Finnish children has become younger. The Finnish Childhood Diabetes Registry Group. Diabetes Care. 1999;22(7):1066-1070. doi:10.2337/diacare.22.7.1066 10388969
123 Pundziute-Lyckå A, Dahlquist G, Nyström L, et al. The incidence of type I diabetes has not increased but shifted to a younger age at diagnosis in the 0–34 years group in Sweden 1983–1998. Diabetologia. 2002;45(6):783-791. doi:10.1007/s00125-002-0845-2 12107721
124 Gardner SG, Bingley PJ, Sawtell PA, Weeks S, Gale EA. Rising incidence of insulin dependent diabetes in children aged under 5 years in the Oxford region: time trend analysis. The Bart’s-Oxford Study Group. BMJ. 1997;315(7110):713-717. doi:10.1136/bmj.315.7110.713 9314756
125 Gale EAM. Spring harvest? Reflections on the rise of type 1 diabetes. Diabetologia. 2005;48(12):2445-2450. doi:10.1007/s00125-005-0028-z 16283244
126 Wilkin TJ. The accelerator hypothesis: weight gain as the missing link between type I and type II diabetes. Diabetologia. 2001;44(7):914-922. doi:10.1007/s001250100548 11508279
127 Dahlquist G. Can we slow the rising incidence of childhood-onset autoimmune diabetes? The overload hypothesis. Diabetologia. 2006;49(1):20-24. doi:10.1007/s00125-005-0076-4 16362279
128 Li Z, Veijola R, Koski E, et al. Childhood height growth rate association with the risk of islet autoimmunity and development of type 1 diabetes. J Clin Endocrinol Metab. 2022;107(6):1520-1528. doi:10.1210/clinem/dgac121 35244713
129 Liu X, Vehik K, Huang Y, et al. Distinct growth phases in early life associated with the risk of type 1 diabetes: the TEDDY study. Diabetes Care. 2020;43(3):556-562. doi:10.2337/dc19-1670 31896601
130 Dabelea D, D’Agostino RB, Jr., Mayer-Davis EJ, et al. Testing the accelerator hypothesis: body size, β-cell function, and age at onset of type 1 (autoimmune) diabetes. Diabetes Care. 2006;29(2):290-294. doi:10.2337/diacare.29.02.06.dc05-1339 16443875
131 Couper JJ, Beresford S, Hirte C, et al. Weight gain in early life predicts risk of islet autoimmunity in children with a first-degree relative with type 1 diabetes. Diabetes Care. 2009;32(1):94-99. doi:10.2337/dc08-0821 18835948
132 Lipman TH, Levitt Katz LE, Ratcliffe SJ, et al. Increasing incidence of type 1 diabetes in youth: twenty years of the Philadelphia Pediatric Diabetes Registry. Diabetes Care. 2013;36(6):1597-1603. doi:10.2337/dc12-0767 23340888
133 Karlberg J. A biologically-oriented mathematical model (ICP) for human growth. Acta Paediatr Scand Suppl. 1989;350:70-94. doi:10.1111/j.1651-2227.1989.tb11199.x 2801108
134 Tse WY, Hindmarsh PC, Brook CG. The infancy-childhood-puberty model of growth: clinical aspects. Acta Paediatr Scand Suppl. 1989;356:38-43. doi:10.1111/j.1651-2227.1989.tb11238.x 2683573
135 Dabelea D, Dolan LM, D’Agostino R, Jr., et al. Association testing of TCF7L2 polymorphisms with type 2 diabetes in multi-ethnic youth. Diabetologia. 2011;54(3):535-539. doi:10.1007/s00125-010-1982-7 21109996
136 Srinivasan S, Chen L, Todd J, et al. The first genome-wide association study for type 2 diabetes in youth: the Progress in Diabetes Genetics in Youth (ProDiGY) Consortium. Diabetes. 2021;70(4):996-1005. doi:10.2337/db20-0443 33479058
137 Kreienkamp RJ, Voight BF, Gloyn AL, Udler MS. Genetics of type 2 diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597726/
138 Ford ES, Williamson DF, Liu S. Weight change and diabetes incidence: findings from a national cohort of US adults. Am J Epidemiol. 1997;146(3):214-222. doi:10.1093/oxfordjournals.aje.a009256 9247005
139 Colditz GA, Willett WC, Rotnitzky A, Manson JE. Weight gain as a risk factor for clinical diabetes mellitus in women. Ann Intern Med. 1995;122(7):481-486. doi:10.7326/0003-4819-122-7-199504010-00001 7872581
140 Cassano PA, Rosner B, Vokonas PS, Weiss ST. Obesity and body fat distribution in relation to the incidence of non-insulin-dependent diabetes mellitus. A prospective cohort study of men in the Normative Aging Study. Am J Epidemiol. 1992;136(12):1474-1486. doi:10.1093/oxfordjournals.aje.a116468 1288277
141 Hazuda HP, Mitchell BD, Haffner SM, Stern MP. Obesity in Mexican American subgroups: findings from the San Antonio Heart Study. Am J Clin Nutr. 1991;53(6 Suppl):1529S-1534S. doi:10.1093/ajcn/53.6.1529S 2031483
142 Feskens EJ, Kromhout D. Effects of body fat and its development over a ten-year period on glucose tolerance in euglycaemic men: the Zutphen Study. Int J Epidemiol. 1989;18(2):368-373. doi:10.1093/ije/18.2.368 2767850
143 Bjerregaard LG, Jensen BW, Ängquist L, Osler M, Sørensen TIA, Baker JL. Change in overweight from childhood to early adulthood and risk of type 2 diabetes. N Engl J Med. 2018;378(14):1302-1312. doi:10.1056/NEJMoa1713231 29617589
144 Park MH, Sovio U, Viner RM, Hardy RJ, Kinra S. Overweight in childhood, adolescence and adulthood and cardiovascular risk in later life: pooled analysis of three British birth cohorts. PLoS One. 2013;8(7):e70684. doi:10.1371/journal.pone.0070684 23894679
145 Yeung EH, Zhang C, Louis GM, Willett WC, Hu FB. Childhood size and life course weight characteristics in association with the risk of incident type 2 diabetes. Diabetes Care. 2010;33(6):1364-1369. doi:10.2337/dc10-0100 20215459
146 Power C, Thomas C. Changes in BMI, duration of overweight and obesity, and glucose metabolism: 45 years of follow-up of a birth cohort. Diabetes Care. 2011;34(9):1986-1991. doi:10.2337/dc10-1482 21775760
147 Moran A, Jacobs DR, Jr., Steinberger J, et al. Insulin resistance during puberty: results from clamp studies in 357 children. Diabetes. 1999;48(10):2039-2044. doi:10.2337/diabetes.48.10.2039 10512371
148 Caprio S, Plewe G, Diamond MP, et al. Increased insulin secretion in puberty: a compensatory response to reductions in insulin sensitivity. J Pediatr. 1989;114(6):963-967. doi:10.1016/s0022-3476(89)80438-x 2524556
149 Hannon TS, Janosky J, Arslanian SA. Longitudinal study of physiologic insulin resistance and metabolic changes of puberty. Pediatr Res. 2006;60(6):759-763. doi:10.1203/01.pdr.0000246097.73031.27 17065576
150 Goran MI, Gower BA. Longitudinal study on pubertal insulin resistance. Diabetes. 2001;50(11):2444-2450. doi:10.2337/diabetes.50.11.2444 11679420
151 Ball GD, Huang TT, Gower BA, et al. Longitudinal changes in insulin sensitivity, insulin secretion, and β-cell function during puberty. J Pediatr. 2006;148(1):16-22. doi:10.1016/j.jpeds.2005.08.059 16423592
152 Sun M, Sun H. Recent prevalence and trends of obesity and metabolic dysfunction-associated steatotic liver disease (MASLD) among US adolescents: 1999 to 2020. Pediatr Obes. 2025;20(5):e70003. doi:10.1111/ijpo.70003 39967492
153 Lange SJ, Kompaniyets L, Freedman DS, et al. Longitudinal trends in body mass index before and during the COVID-19 pandemic among persons aged 2-19 years—United States, 2018–2020. MMWR Morb Mortal Wkly Rep. 2021;70(37):1278-1283. doi:10.15585/mmwr.mm7037a3 34529635
154 Woolford SJ, Sidell M, Li X, et al. Changes in body mass index among children and adolescents during the COVID-19 pandemic. JAMA. 2021;326(14):1434-1436. doi:10.1001/jama.2021.15036 34448817
155 Jenssen BP, Kelly MK, Shu D, et al. Trends and persistent disparities in child obesity during the COVID-19 pandemic. Child Obes. 2024;20(5):366-370. doi:10.1089/chi.2022.0205 37222743
156 Gayatri M, Dwi Puspitasari M. The impact of COVID-19 pandemic on family well-being: a literature review. Family Journal. 2023;31(4):606-613. doi:10.1177/10664807221131
157 Pinhas-Hamiel O, Zeitler P. “Who is the wise man?—The one who foresees consequences” Childhood obesity, new associated comorbidity and prevention. Prev Med. 2000;31(6):702-705. doi:10.1006/pmed.2000.0752 11133337
158 Ebbeling CB, Pawlak DB, Ludwig DS. Childhood obesity: public-health crisis, common sense cure. Lancet. 2002;360(9331):473-482. doi:10.1016/S0140-6736(02)09678-2 12241736
159 Food Nutrition Service (FNS) USDA. Cooperation in USDA studies and evaluations, and full use of federal funds in nutrition assistance programs nondiscretionary provisions of the Healthy, Hunger-Free Kids Act of 2010, Public Law 111-296. Final rule. Fed Regist. 2011;76(125):37979-37983. https://www.govinfo.gov/content/pkg/FR-2011-06-29/pdf/FR-2011-06-29.pdf 21721318
160 Wolf AM, Gortmaker SL, Cheung L, Gray HM, Herzog DB, Colditz GA. Activity, inactivity, and obesity: racial, ethnic, and age differences among schoolgirls. Am J Public Health. 1993;83(11):1625-1627. doi:10.2105/ajph.83.11.1625 8238692
161 Kann L, McManus T, Harris WA, et al. Youth risk behavior surveillance—United States, 2017. MMWR Surveill Summ. 2018;67(8):1-114. doi:10.15585/mmwr.ss6708a1 29902162
162 Centers for Disease Control and Prevention (CDC). High school youth risk behavior survey data. 1991–2023. Accessed February 26, 2025. http://yrbs-explorer.services.cdc.gov/.
163 Eaton DK, Kann L, Kinchen S, et al. Youth risk behavior surveillance—United States, 2011. MMWR Surveill Summ. 2012;61(4):1-162. https://www.cdc.gov/mmwr/preview/mmwrhtml/ss6104a1.htm 22673000
164 Nesmith JD. Type 2 diabetes mellitus in children and adolescents. Pediatr Rev. 2001;22(5):147-152. doi:10.1542/pir.22-5-147 11331736
165 Ogden CL, Carroll MD, Curtin LR, McDowell MA, Tabak CJ, Flegal KM. Prevalence of overweight and obesity in the United States, 1999–2004. JAMA. 2006;295(13):1549-1555. doi:10.1001/jama.295.13.1549 16595758
166 Berman LJ, Weigensberg MJ, Spruijt-Metz D. Physical activity is related to insulin sensitivity in children and adolescents, independent of adiposity: a review of the literature. Diabetes Metab Res Rev. 2012;28(5):395-408. doi:10.1002/dmrr.2292 22389103
167 Hales CN, Barker DJ, Clark PM, et al. Fetal and infant growth and impaired glucose tolerance at age 64. BMJ. 1991;303(6809):1019-1022. doi:10.1136/bmj.303.6809.1019 1954451
168 Dabelea D, Pettitt DJ, Hanson RL, Imperatore G, Bennett PH, Knowler WC. Birth weight, type 2 diabetes, and insulin resistance in Pima Indian children and young adults. Diabetes Care. 1999;22(6):944-950. doi:10.2337/diacare.22.6.944 10372247
169 Gluckman PD, Hanson MA. Developmental and epigenetic pathways to obesity: an evolutionary-developmental perspective. Int J Obes (Lond). 2008;32(Suppl 7):S62-S71. doi:10.1038/ijo.2008.240 19136993
170 Ozanne SE, Hales CN. Pre- and early postnatal nongenetic determinants of type 2 diabetes. Expert Rev Mol Med. 2002;4(24):1-14. doi:10.1017/S1462399402005240 14987383
171 Pettitt DJ, Baird HR, Aleck KA, Bennett PH, Knowler WC. Excessive obesity in offspring of Pima Indian women with diabetes during pregnancy. N Engl J Med. 1983;308(5):242-245. doi:10.1056/NEJM198302033080502 6848933
172 Dabelea D, Knowler WC, Pettitt DJ. Effect of diabetes in pregnancy on offspring: follow-up research in the Pima Indians. J Matern Fetal Med. 2000;9(1):83-88. doi:10.1002/(SICI)1520-6661(200001/02)9:1<83::AID-MFM17>3.0.CO;2-O 10757442
173 Pettitt DJ, Knowler WC. Diabetes and obesity in the Pima Indians: a cross-generational vicious cycle. J Obesity Weight Regulation. 1988;7(2):61-75.
174 Pettitt DJ, Aleck KA, Baird HR, Carraher MJ, Bennett PH, Knowler WC. Congenital susceptibility to NIDDM. Role of intrauterine environment. Diabetes. 1988;37(5):622-628. doi:10.2337/diab.37.5.622 3360218
175 Pettitt DJ, Bennett PH, Everhart J, Kunzelman CL, Knowler WC. High plasma glucose concentrations in normal weight offspring of diabetic women. Diabetes Res Clin Pract. 1985;1(Suppl 1):S445.
176 Dabelea D, Hanson RL, Lindsay RS, et al. Intrauterine exposure to diabetes conveys risks for type 2 diabetes and obesity: a study of discordant sibships. Diabetes. 2000;49(12):2208-2211. doi:10.2337/diabetes.49.12.2208 11118027
177 Dabelea D, Mayer-Davis EJ, Lamichhane AP, et al. Association of intrauterine exposure to maternal diabetes and obesity with type 2 diabetes in youth: the SEARCH Case-Control Study. Diabetes Care. 2008;31(7):1422-1426. doi:10.2337/dc07-2417 18375420
178 Kramer MS, Barr RG, Leduc DG, Boisjoly C, Pless IB. Infant determinants of childhood weight and adiposity. J Pediatr. 1985;107(1):104-107. doi:10.1016/s0022-3476(85)80627-2 4009326
179 Burke V, Beilin LJ, Simmer K, et al. Breastfeeding and overweight: longitudinal analysis in an Australian birth cohort. J Pediatr. 2005;147(1):56-61. doi:10.1016/j.jpeds.2005.03.038 16027696
180 Pettitt DJ, Forman MR, Hanson RL, Knowler WC, Bennett PH. Breastfeeding and incidence of non-insulin-dependent diabetes mellitus in Pima Indians. Lancet. 1997;350(9072):166-168. doi:10.1016/S0140-6736(96)12103-6 9250183
181 Mayer-Davis EJ, Dabelea D, Lamichhane AP, et al. Breast-feeding and type 2 diabetes in the youth of three ethnic groups: the SEARCH for Diabetes in Youth Case-Control Study. Diabetes Care. 2008;31(3):470-475. doi:10.2337/dc07-1321 18071004
182 Crume TL, Ogden L, Maligie M, et al. Long-term impact of neonatal breastfeeding on childhood adiposity and fat distribution among children exposed to diabetes in utero. Diabetes Care. 2011;34(3):641-645. doi:10.2337/dc10-1716 21357361
183 Dahlquist G, Källén B. Mortality in childhood-onset type 1 diabetes: a population-based study. Diabetes Care. 2005;28(10):2384-2387. doi:10.2337/diacare.28.10.2384 16186267
184 Dabelea D, Stafford JM, Mayer-Davis EJ, et al. Association of type 1 diabetes vs type 2 diabetes diagnosed during childhood and adolescence with complications during teenage years and young adulthood. JAMA. 2017;317(8):825-835. doi:10.1001/jama.2017.0686 28245334
185 TODAY Study Group, Bjornstad P, Drews KL, et al. Long-term complications in youth-onset type 2 diabetes. N Engl J Med. 2021;385(5):416-426. doi:10.1056/NEJMoa2100165 34320286
186 Maniatis AK, Goehrig SH, Gao D, Rewers A, Walravens P, Klingensmith GJ. Increased incidence and severity of diabetic ketoacidosis among uninsured children with newly diagnosed type 1 diabetes mellitus. Pediatr Diabetes. 2005;6(2):79-83. doi:10.1111/j.1399-543X.2005.00096.x 15963034
187 Quinn M, Fleischman A, Rosner B, Nigrin DJ, Wolfsdorf JI. Characteristics at diagnosis of type 1 diabetes in children younger than 6 years. J Pediatr. 2006;148(3):366-371. doi:10.1016/j.jpeds.2005.10.029 16615969
188 Mallare JT, Cordice CC, Ryan BA, Carey DE, Kreitzer PM, Frank GR. Identifying risk factors for the development of diabetic ketoacidosis in new onset type 1 diabetes mellitus. Clin Pediatr (Phila). 2003;42(7):591-597. doi:10.1177/000992280304200704 14552517
189 Liu LL, Yi JP, Beyer J, et al. Type 1 and type 2 diabetes in Asian and Pacific Islander U.S. youth: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2009;32(Suppl 2):S133-S140. doi:10.2337/dc09-S205 19246578
190 Lawrence JM, Mayer-Davis EJ, Reynolds K, et al. Diabetes in Hispanic American youth: prevalence, incidence, demographics, and clinical characteristics: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2009;32(Suppl 2):S123-S132. doi:10.2337/dc09-S204 19246577
191 Mayer-Davis EJ, Beyer J, Bell RA, et al. Diabetes in African American youth: prevalence, incidence, and clinical characteristics: the SEARCH for Diabetes in Youth study. Diabetes Care. 2009;32(Suppl 2):S112-S122. doi:10.2337/dc09-S203 19246576
192 Bell RA, Mayer-Davis EJ, Beyer JW, et al. Diabetes in non-Hispanic White youth: prevalence, incidence, and clinical characteristics: the SEARCH for Diabetes in Youth study. Diabetes Care. 2009;32(Suppl 2):S102-S111. doi:10.2337/dc09-S202 19246575
193 Willi SM, Miller KM, DiMeglio LA, et al. Racial-ethnic disparities in management and outcomes among children with type 1 diabetes. Pediatrics. 2015;135(3):424-434. doi:10.1542/peds.2014-1774 25687140
194 Cengiz E, Xing D, Wong JC, et al. Severe hypoglycemia and diabetic ketoacidosis among youth with type 1 diabetes in the T1D Exchange Clinic Registry. Pediatr Diabetes. 2013;14(6):447-454. doi:10.1111/pedi.12030 23469984
195 Rewers A, Chase HP, Mackenzie T, et al. Predictors of acute complications in children with type 1 diabetes. JAMA. 2002;287(19):2511-2518. doi:10.1001/jama.287.19.2511 12020331
196 Effect of intensive diabetes treatment on the development and progression of long-term complications in adolescents with insulin-dependent diabetes mellitus: Diabetes Control and Complications Trial. Diabetes Control and Complications Trial Research Group. J Pediatr. 1994;125(2):177-188. doi:10.1016/s0022-3476(94)70190-3 8040759
197 Paris CA, Imperatore G, Klingensmith G, et al. Predictors of insulin regimens and impact on outcomes in youth with type 1 diabetes: the SEARCH for Diabetes in Youth study. J Pediatr. 2009;155(2):183-189.e1. doi:10.1016/j.jpeds.2009.01.063 19394043
198 Samuelsson U, Stenhammar L. Clinical characteristics at onset of type 1 diabetes in children diagnosed between 1977 and 2001 in the south-east region of Sweden. Diabetes Res Clin Pract. 2005;68(1):49-55. doi:10.1016/j.diabres.2004.08.002 15811565
199 Hekkala A, Reunanen A, Koski M, Knip M, Veijola R, Finnish Pediatric Diabetes Register. Age-related differences in the frequency of ketoacidosis at diagnosis of type 1 diabetes in children and adolescents. Diabetes Care. 2010;33(7):1500-1502. doi:10.2337/dc09-2344 20413519
200 Hekkala A, Knip M, Veijola R. Ketoacidosis at diagnosis of type 1 diabetes in children in northern Finland: temporal changes over 20 years. Diabetes Care. 2007;30(4):861-866. doi:10.2337/dc06-2281 17392547
201 Neu A, Hofer SE, Karges B, et al. Ketoacidosis at diabetes onset is still frequent in children and adolescents: a multicenter analysis of 14,664 patients from 106 institutions. Diabetes Care. 2009;32(9):1647-1648. doi:10.2337/dc09-0553 19549730
202 Schober E, Rami B, Waldhoer T, Austrian Diabetes Incidence Study Group. Diabetic ketoacidosis at diagnosis in Austrian children in 1989–2008: a population-based analysis. Diabetologia. 2010;53(6):1057-1061. doi:10.1007/s00125-010-1704-1 20213235
203 Rosenbauer J, Dost A, Karges B, et al. Improved metabolic control in children and adolescents with type 1 diabetes: a trend analysis using prospective multicenter data from Germany and Austria. Diabetes Care. 2012;35(1):80-86. doi:10.2337/dc11-0993 22074726
204 Zimmermann AT, Lanzinger S, Kummernes SJ, et al. Treatment regimens and glycaemic outcomes in more than 100 000 children with type 1 diabetes (2013–22): a longitudinal analysis of data from paediatric diabetes registries. Lancet Diabetes Endocrinol. 2025;13(1):47-56. doi:10.1016/S2213-8587(24)00279-1 39622257
205 Curtis JR, To T, Muirhead S, Cummings E, Daneman D. Recent trends in hospitalization for diabetic ketoacidosis in Ontario children. Diabetes Care. 2002;25(9):1591-1596. doi:10.2337/diacare.25.9.1591 12196432
206 Alaghehbandan R, Collins KD, Newhook LA, MacDonald D. Childhood type 1 diabetes mellitus in Newfoundland and Labrador, Canada. Diabetes Res Clin Pract. 2006;74(1):82-89. doi:10.1016/j.diabres.2006.03.001 16621109
207 Klingensmith GJ, Tamborlane WV, Wood J, et al. Diabetic ketoacidosis at diabetes onset: still an all too common threat in youth. J Pediatr. 2013;162(2):330-334.e1. doi:10.1016/j.jpeds.2012.06.058 22901739
208 Jensen ET, Stafford JM, Saydah S, et al. Increase in prevalence of diabetic ketoacidosis at diagnosis among youth with type 1 diabetes: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2021;44(7):1573-1578. doi:10.2337/dc20-0389 34099516
209 Cherubini V, Grimsmann JM, Åkesson K, et al. Temporal trends in diabetic ketoacidosis at diagnosis of paediatric type 1 diabetes between 2006 and 2016: results from 13 countries in three continents. Diabetologia. 2020;63(8):1530-1541. doi:10.1007/s00125-020-05152-1 32382815
210 Elding Larsson H, Vehik K, Bell R, et al. Reduced prevalence of diabetic ketoacidosis at diagnosis of type 1 diabetes in young children participating in longitudinal follow-up. Diabetes Care. 2011;34(11):2347-2352. doi:10.2337/dc11-1026 21972409
211 Jacobsen LM, Vehik K, Veijola R, et al. Heterogeneity of DKA incidence and age-specific clinical characteristics in children diagnosed with type 1 diabetes in the TEDDY study. Diabetes Care. 2022;45(3):624-633. doi:10.2337/dc21-0422 35043162
212 Duca LM, Reboussin BA, Pihoker C, et al. Diabetic ketoacidosis at diagnosis of type 1 diabetes and glycemic control over time: the SEARCH for Diabetes in Youth study. Pediatr Diabetes. 2019;20(2):172-179. doi:10.1111/pedi.12809 30556249
213 Zdravkovic V, Daneman D, Hamilton J. Presentation and course of type 2 diabetes in youth in a large multi-ethnic city. Diabet Med. 2004;21(10):1144-1148. doi:10.1111/j.1464-5491.2004.01297.x 15384964
214 Praveen PA, Hockett CW, Ong TC, et al. Diabetic ketoacidosis at diagnosis among youth with type 1 and type 2 diabetes: results from SEARCH (United States) and YDR (India) registries. Pediatr Diabetes. 2021;22(1):40-46. doi:10.1111/pedi.12979 31943641
215 Pinhas-Hamiel O, Zeitler P. Acute and chronic complications of type 2 diabetes mellitus in children and adolescents. Lancet. 2007;369(9575):1823-1831. doi:10.1016/S0140-6736(07)60821-6 17531891
216 Schmitt J, Rahman AF, Ashraf A. Concurrent diabetic ketoacidosis with hyperosmolality and/or severe hyperglycemia in youth with type 2 diabetes. Endocrinol Diabetes Metab. 2020;3(3):e00160. doi:10.1002/edm2.160 32704574
217 D’Souza D, Empringham J, Pechlivanoglou P, Uleryk EM, Cohen E, Shulman R. Incidence of diabetes in children and adolescents during the COVID-19 pandemic: a systematic review and meta-analysis. JAMA Netw Open. 2023;6(6):e2321281. doi:10.1001/jamanetworkopen.2023.21281 37389869
218 Chao LC, Vidmar AP, Georgia S. Spike in diabetic ketoacidosis rates in pediatric type 2 diabetes during the COVID-19 pandemic. Diabetes Care. 2021;44(6):1451-1453. doi:10.2337/dc20-2733 33905347
219 Abraham MB, Karges B, Dovc K, et al. ISPAD Clinical Practice Consensus Guidelines 2022: Assessment and management of hypoglycemia in children and adolescents with diabetes. Pediatr Diabetes. 2022;23(8):1322-1340. doi:10.1111/pedi.13443 36537534
220 American Diabetes Association Professional Practice Committee. 6. Glycemic Goals and Hypoglycemia: Standards of Care in Diabetes-2025. Diabetes Care. 2025;48(1 Suppl 1):S128-S145. doi:10.2337/dc25-S006 39651981
221 Seaquist ER, Anderson J, Childs B, et al. Hypoglycemia and Diabetes: a report of a workgroup of the American Diabetes Association and the Endocrine Society. Diabetes Care. 2013;36(5):1384-1395. doi:10.2337/dc12-2480 23589542
222 Allen C, LeCaire T, Palta M, et al. Risk factors for frequent and severe hypoglycemia in type 1 diabetes. Diabetes Care. 2001;24(11):1878-1881. doi:10.2337/diacare.24.11.1878 11679450
223 Katz ML, Volkening LK, Anderson BJ, Laffel LM. Contemporary rates of severe hypoglycaemia in youth with type 1 diabetes: variability by insulin regimen. Diabet Med. 2012;29(7):926-932. doi:10.1111/j.1464-5491.2012.03646.x 22417321
224 Ly TT, Gallego PH, Davis EA, Jones TW. Impaired awareness of hypoglycemia in a population-based sample of children and adolescents with type 1 diabetes. Diabetes Care. 2009;32(10):1802-1806. doi:10.2337/dc09-0541 19587370
225 Hypoglycemia in the Diabetes Control and Complications Trial. The Diabetes Control and Complications Trial Research Group. Diabetes. 1997;46(2):271-286. doi:10.2337/diab.46.2.271 9000705
226 Gubitosi-Klug RA, Braffett BH, White NH, et al. Risk of severe hypoglycemia in type 1 diabetes over 30 years of follow-up in the DCCT/EDIC Study. Diabetes Care. 2017;40(8):1010-1016. doi:10.2337/dc16-2723 28550194
227 Saydah S, Imperatore G, Divers J, et al. Occurrence of severe hypoglycaemic events among US youth and young adults with type 1 or type 2 diabetes. Endocrinol Diabetes Metab. 2019;2(2):e00057. doi:10.1002/edm2.57 31008365
228 Strategies to Enhance New CGM Use in Early Childhood (SENCE) Study Group. A randomized clinical trial assessing continuous glucose monitoring (CGM) use with standardized education with or without a family behavioral intervention compared with fingerstick blood glucose monitoring in very young children with type 1 diabetes. Diabetes Care. 2021;44(2):464-472. doi:10.2337/dc20-1060 33334807
229 Tauschmann M, Hermann JM, Freiberg C, et al. Reduction in diabetic ketoacidosis and severe hypoglycemia in pediatric type 1 diabetes during the first year of continuous glucose monitoring: a multicenter analysis of 3,553 subjects from the DPV registry. Diabetes Care. 2020;43(3):e40-e42. doi:10.2337/dc19-1358 31969340
230 Karges B, Tittel SR, Bey A, et al. Continuous glucose monitoring versus blood glucose monitoring for risk of severe hypoglycaemia and diabetic ketoacidosis in children, adolescents, and young adults with type 1 diabetes: a population-based study. Lancet Diabetes Endocrinol. 2023;11(5):314-323. doi:10.1016/S2213-8587(23)00061-X 37004710
231 Johnson SR, Holmes-Walker DJ, Chee M, et al. Universal subsidized continuous glucose monitoring funding for young people with type 1 diabetes: uptake and outcomes over 2 years, a population-based study. Diabetes Care. 2022;45(2):391-397. doi:10.2337/dc21-1666 34872983
232 Gonder-Frederick L, Zrebiec J, Bauchowitz A, et al. Detection of hypoglycemia by children with type 1 diabetes 6 to 11 years of age and their parents: a field study. Pediatrics. 2008;121(3):e489-e495. doi:10.1542/peds.2007-0808 18310169
233 Ryan CM. Why is cognitive dysfunction associated with the development of diabetes early in life? The diathesis hypothesis. Pediatr Diabetes. 2006;7(5):289-297. doi:10.1111/j.1399-5448.2006.00206.x 17054452
234 Hershey T, Perantie DC, Wu J, Weaver PM, Black KJ, White NH. Hippocampal volumes in youth with type 1 diabetes. Diabetes. 2010;59(1):236-241. doi:10.2337/db09-1117 19833895
235 Aye T, Reiss AL, Kesler S, et al. The feasibility of detecting neuropsychologic and neuroanatomic effects of type 1 diabetes in young children. Diabetes Care. 2011;34(7):1458-1462. doi:10.2337/dc10-2164 21562318
236 Patterson CC, Dahlquist G, Harjutsalo V, et al. Early mortality in EURODIAB population-based cohorts of type 1 diabetes diagnosed in childhood since 1989. Diabetologia. 2007;50(12):2439-2442. doi:10.1007/s00125-007-0824-8 17901942
237 Feltbower RG, Bodansky HJ, Patterson CC, et al. Acute complications and drug misuse are important causes of death for children and young adults with type 1 diabetes: results from the Yorkshire Register of diabetes in children and young adults. Diabetes Care. 2008;31(5):922-926. doi:10.2337/dc07-2029 18285550
238 Karges B, Rosenbauer J, Stahl-Pehe A, et al. Hybrid closed-loop insulin therapy and risk of severe hypoglycaemia and diabetic ketoacidosis in young people (aged 2–20 years) with type 1 diabetes: a population-based study. Lancet Diabetes Endocrinol. 2025;13(2):88-96. doi:10.1016/S2213-8587(24)00284-5 39701114
239 TODAY Study Group. Safety and tolerability of the treatment of youth-onset type 2 diabetes: the TODAY experience. Diabetes Care. 2013;36(6):1765-1771. doi:10.2337/dc12-2390 23704676
240 LeCaire T, Palta M, Zhang H, Allen C, Klein R, D’Alessio D. Lower-than-expected prevalence and severity of retinopathy in an incident cohort followed during the first 4–14 years of type 1 diabetes: the Wisconsin Diabetes Registry Study. Am J Epidemiol. 2006;164(2):143-150. doi:10.1093/aje/kwj166 16731577
241 LeCaire TJ, Palta M, Klein R, Klein BE, Cruickshanks KJ. Assessing progress in retinopathy outcomes in type 1 diabetes: comparing findings from the Wisconsin Diabetes Registry Study and the Wisconsin Epidemiologic Study of Diabetic Retinopathy. Diabetes Care. 2013;36(3):631-637. doi:10.2337/dc12-0863 23193204
242 Pambianco G, Costacou T, Ellis D, Becker DJ, Klein R, Orchard TJ. The 30-year natural history of type 1 diabetes complications: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes. 2006;55(5):1463-1469. doi:10.2337/db05-1423 16644706
243 Nordwall M, Bojestig M, Arnqvist HJ, Ludvigsson J. Declining incidence of severe retinopathy and persisting decrease of nephropathy in an unselected population of type 1 diabetes—the Linköping Diabetes Complications Study. Diabetologia. 2004;47(7):1266-1272. doi:10.1007/s00125-004-1431-6 15235773
244 Downie E, Craig ME, Hing S, Cusumano J, Chan AK, Donaghue KC. Continued reduction in the prevalence of retinopathy in adolescents with type 1 diabetes: role of insulin therapy and glycemic control. Diabetes Care. 2011;34(11):2368-2373. doi:10.2337/dc11-0102 22025782
245 Mohsin F, Craig ME, Cusumano J, et al. Discordant trends in microvascular complications in adolescents with type 1 diabetes from 1990 to 2002. Diabetes Care. 2005;28(8):1974-1980. doi:10.2337/diacare.28.8.1974 16043741
246 White NH, Cleary PA, Dahms W, et al. Beneficial effects of intensive therapy of diabetes during adolescence: outcomes after the conclusion of the Diabetes Control and Complications Trial (DCCT). J Pediatr. 2001;139(6):804-812. doi:10.1067/mpd.2001.118887 11743505
247 White NH, Sun W, Cleary PA, et al. Effect of prior intensive therapy in type 1 diabetes on 10-year progression of retinopathy in the DCCT/EDIC: comparison of adults and adolescents. Diabetes. 2010;59(5):1244-1253. doi:10.2337/db09-1216 20150283
248 Lin T, Gubitosi-Klug RA, Channa R, Wolf RM. Pediatric diabetic retinopathy: updates in prevalence, risk factors, screening, and management. Curr Diab Rep. 2021;21(12):56. doi:10.1007/s11892-021-01436-x 34902076
249 Cho YH, Craig ME, Hing S, et al. Microvascular complications assessment in adolescents with 2- to 5-yr duration of type 1 diabetes from 1990 to 2006. Pediatr Diabetes. 2011;12(8):682-689. doi:10.1111/j.1399-5448.2011.00762.x 21435138
250 Thomas CG, Channa R, Prichett L, Liu TYA, Abramoff MD, Wolf RM. Racial/ethnic disparities and barriers to diabetic retinopathy screening in youths. JAMA Ophthalmol. 2021;139(7):791-795. doi:10.1001/jamaophthalmol.2021.1551 34042939
251 Dumser SM, Ratcliffe SJ, Langdon DR, Murphy KM, Lipman TH. Racial disparities in screening for diabetic retinopathy in youth with type 1 diabetes. Diabetes Res Clin Pract. 2013;101(1):e3-e5. doi:10.1016/j.diabres.2013.03.009 23642967
252 Jensen ET, Rigdon J, Rezaei KA, et al. Prevalence, progression, and modifiable risk factors for diabetic retinopathy in youth and young adults with youth-onset type 1 and type 2 diabetes: the SEARCH for Diabetes in Youth study. Diabetes Care. 2023;46(6):1252-1260. doi:10.2337/dc22-2503 37043887
253 Dabelea D, Sauder KA, Jensen ET, et al. Twenty years of pediatric diabetes surveillance: what do we know and why it matters. Ann N Y Acad Sci. 2021;1495(1):99-120. doi:10.1111/nyas.14573 33543783
254 Mayer-Davis EJ, Davis C, Saadine J, et al. Diabetic retinopathy in the SEARCH for Diabetes in Youth cohort: a pilot study. Diabet Med. 2012;29(9):1148-1152. doi:10.1111/j.1464-5491.2012.03591.x 22269205
255 TODAY Study Group. Retinopathy in youth with type 2 diabetes participating in the TODAY clinical trial. Diabetes Care. 2013;36(6):1772-1774. doi:10.2337/dc12-2387 23704677
256 TODAY Study Group. Development and progression of diabetic retinopathy in adolescents and young adults with type 2 diabetes: results from the TODAY study. Diabetes Care. 2021;45(5):1049-1055. doi:10.2337/dc21-1072 34531310
257 Zhang X, Saaddine JB, Chou CF, et al. Prevalence of diabetic retinopathy in the United States, 2005–2008. JAMA. 2010;304(6):649-656. doi:10.1001/jama.2010.1111 20699456
258 Dart AB, Martens PJ, Rigatto C, Brownell MD, Dean HJ, Sellers EA. Earlier onset of complications in youth with type 2 diabetes. Diabetes Care. 2014;37(2):436-443. doi:10.2337/dc13-0954 24130346
259 Krakoff J, Lindsay RS, Looker HC, Nelson RG, Hanson RL, Knowler WC. Incidence of retinopathy and nephropathy in youth-onset compared with adult-onset type 2 diabetes. Diabetes Care. 2003;26(1):76-81. doi:10.2337/diacare.26.1.76 12502661
260 Constantino MI, Molyneaux L, Limacher-Gisler F, et al. Long-term complications and mortality in young-onset diabetes: type 2 diabetes is more hazardous and lethal than type 1 diabetes. Diabetes Care. 2013;36(12):3863-3869. doi:10.2337/dc12-2455 23846814
261 Ek AE, Samuelsson U, Janson A, Carlsson A, Elimam A, Marcus C. Microalbuminuria and retinopathy in adolescents and young adults with type 1 and type 2 diabetes. Pediatr Diabetes. 2020;21(7):1310-1321. doi:10.1111/pedi.13074 32613727
262 Looker HC, Krakoff J, Knowler WC, Bennett PH, Klein R, Hanson RL. Longitudinal studies of incidence and progression of diabetic retinopathy assessed by retinal photography in Pima Indians. Diabetes Care. 2003;26(2):320-326. doi:10.2337/diacare.26.2.320 12547856
263 Dwyer JP, Lewis JB. Nonproteinuric diabetic nephropathy: when diabetics don’t read the textbook. Med Clin North Am. 2013;97(1):53-58. doi:10.1016/j.mcna.2012.10.006 23290729
264 Rigalleau V, Lasseur C, Raffaitin C, et al. Normoalbuminuric renal-insufficient diabetic patients: a lower-risk group. Diabetes Care. 2007;30(8):2034-2039. doi:10.2337/dc07-0140 17485574
265 Mottl AK, Kwon KS, Mauer M, Mayer-Davis EJ, Hogan SL, Kshirsagar AV. Normoalbuminuric diabetic kidney disease in the U.S. population. J Diabetes Complications. 2013;27(2):123-127. doi:10.1016/j.jdiacomp.2012.09.010 23182925
266 Maahs DM, Snively BM, Bell RA, et al. Higher prevalence of elevated albumin excretion in youth with type 2 than type 1 diabetes: the SEARCH for Diabetes in Youth study. Diabetes Care. 2007;30(10):2593-2598. doi:10.2337/dc07-0450 17630264
267 Daniels M, DuBose SN, Maahs DM, et al. Factors associated with microalbuminuria in 7,549 children and adolescents with type 1 diabetes in the T1D Exchange Clinic Registry. Diabetes Care. 2013;36(9):2639-2645. doi:10.2337/dc12-2192 23610082
268 Dart AB, Sellers EA, Martens PJ, Rigatto C, Brownell MD, Dean HJ. High burden of kidney disease in youth-onset type 2 diabetes. Diabetes Care. 2012;35(6):1265-1271. doi:10.2337/dc11-2312 22432116
269 Klein R, Klein BE, Moss SE, Cruickshanks KJ, Brazy PC. The 10-year incidence of renal insufficiency in people with type 1 diabetes. Diabetes Care. 1999;22(5):743-751. doi:10.2337/diacare.22.5.743 10332675
270 Orchard TJ, Chang Y-F, Ferrell RE, Petro N, Ellis DE. Nephropathy in type 1 diabetes: a manifestation of insulin resistance and multiple genetic susceptibilities? Further evidence from the Pittsburgh Epidemiology of Diabetes Complication Study. Kidney Int. 2002;62(3):963-970. doi:10.1046/j.1523-1755.2002.00507.x 12164879
271 Lloyd CE, Stephenson J, Fuller JH, Orchard TJ. A comparison of renal disease across two continents; the Epidemiology of Diabetes Complications Study and the EURODIAB IDDM Complications Study. Diabetes Care. 1996;19(3):219-225. doi:10.2337/diacare.19.3.219 8742565
272 Perkins BA, Ficociello LH, Silva KH, Finkelstein DM, Warram JH, Krolewski AS. Regression of microalbuminuria in type 1 diabetes. N Engl J Med. 2003;348(23):2285-2293. doi:10.1056/NEJMoa021835 12788992
273 Gallego PH, Bulsara MK, Frazer F, Lafferty AR, Davis EA, Jones TW. Prevalence and risk factors for microalbuminuria in a population-based sample of children and adolescents with T1DM in Western Australia. Pediatr Diabetes. 2006;7(3):165-172. doi:10.1111/j.1399-543X.2006.00164.x 16787524
274 Pambianco G, Costacou T, Orchard TJ. The prediction of major outcomes of type 1 diabetes: a 12-year prospective evaluation of three separate definitions of the metabolic syndrome and their components and estimated glucose disposal rate: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes Care. 2007;30(5):1248-1254. doi:10.2337/dc06-2053 17303788
275 Bjornstad P, Maahs DM, Johnson RJ, Rewers M, Snell-Bergeon JK. Estimated insulin sensitivity predicts regression of albuminuria in type 1 diabetes. Diabet Med. 2015;32(2):257-261. doi:10.1111/dme.12572 25303233
276 Bjornstad P, Snell-Bergeon JK, Rewers M, et al. Early diabetic nephropathy: a complication of reduced insulin sensitivity in type 1 diabetes. Diabetes Care. 2013;36(11):3678-3683. doi:10.2337/dc13-0631 24026551
277 Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) Research Group, Nathan DM, Zinman B, et al. Modern-day clinical course of type 1 diabetes mellitus after 30 years’ duration: the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications and Pittsburgh Epidemiology of Diabetes Complications experience (1983–2005). Arch Intern Med. 2009;169(14):1307-1316. doi:10.1001/archinternmed.2009.193 19636033
278 Bjornstad P, Choi YJ, Platnick C, et al. Insulin secretion, sensitivity, and kidney function in young individuals with type 2 diabetes. Diabetes Care. 2024;47(3):409-417. doi:10.2337/dc23-1818 38153805
279 Cioana M, Deng J, Hou M, et al. Prevalence of hypertension and albuminuria in pediatric type 2 diabetes: a systematic review and meta-analysis. JAMA Netw Open. 2021;4(4):e216069. doi:10.1001/jamanetworkopen.2021.6069 33929524
280 Nelson RG, Kunzelman CL, Pettitt DJ, Saad MF, Bennett PH, Knowler WC. Albuminuria in type 2 (non-insulin-dependent) diabetes mellitus and impaired glucose tolerance in Pima Indians. Diabetologia. 1989;32(12):870-876. doi:10.1007/BF00297452 2612758
281 Bjornstad P, Nehus E, El Ghormli L, et al. Insulin sensitivity and diabetic kidney disease in children and adolescents with type 2 diabetes: an observational analysis of data from the TODAY clinical trial. Am J Kidney Dis. 2018;71(1):65-74. doi:10.1053/j.ajkd.2017.07.015 29157731
282 El Ghormli L, Wen H, Uschner D, et al. Trajectories of eGFR and risk of albuminuria in youth with type 2 diabetes: results from the TODAY cohort study. Pediatr Nephrol. 2023;38(12):4137-4144. doi:10.1007/s00467-023-06044-3 37434027
283 Westreich KD, Isom S, Divers J, et al. Trajectories in estimated glomerular filtration rate in youth-onset type 1 and type 2 diabetes: the SEARCH for Diabetes in Youth study. J Diabetes Complications. 2021;35(2):107768. doi:10.1016/j.jdiacomp.2020.107768 33168393
284 Stefansson VTN, Nair V, Melsom T, et al. Molecular programs associated with glomerular hyperfiltration in early diabetic kidney disease. Kidney Int. 2022;102(6):1345-1358. doi:10.1016/j.kint.2022.07.033 36055599
285 Pavkov ME, Bennett PH, Knowler WC, Krakoff J, Sievers ML, Nelson RG. Effect of youth-onset type 2 diabetes mellitus on incidence of end-stage renal disease and mortality in young and middle-aged Pima Indians. JAMA. 2006;296(4):421-426. doi:10.1001/jama.296.4.421 16868300
286 Looker HC, Pyle L, Vigers T, et al. Structural lesions on kidney biopsy in youth-onset and adult-onset type 2 diabetes. Diabetes Care. 2022;45(2):436-443. doi:10.2337/dc21-1688 35006272
287 Yokoyama H, Okudaira M, Otani T, et al. Higher incidence of diabetic nephropathy in type 2 than in type 1 diabetes in early-onset diabetes in Japan. Kidney Int. 2000;58(1):302-311. doi:10.1046/j.1523-1755.2000.00166.x 10886575
288 Eppens MC, Craig ME, Cusumano J, et al. Prevalence of diabetes complications in adolescents with type 2 compared with type 1 diabetes. Diabetes Care. 2006;29(6):1300-1306. doi:10.2337/dc05-2470 16732012
289 Sellers EA, Blydt-Hansen TD, Dean HJ, Gibson IW, Birk PE, Ogborn M. Macroalbuminuria and renal pathology in First Nation youth with type 2 diabetes. Diabetes Care. 2009;32(5):786-90. doi:10.2337/dc08-1828 19228860
290 TODAY Study Group. Rapid rise in hypertension and nephropathy in youth with type 2 diabetes: the TODAY clinical trial. Diabetes Care. 2013;36(6):1735-1741. doi:10.2337/dc12-2420 23704672
291 TODAY Study Group. Effects of metabolic factors, race-ethnicity, and sex on the development of nephropathy in adolescents and young adults with type 2 diabetes: results from the TODAY study. Diabetes Care. 2021;45(5):1056-1064. doi:10.2337/dc21-1085 34531309
292 Komenda P, Lavallee B, Ferguson TW, et al. The prevalence of CKD in rural Canadian Indigenous peoples: results from the First Nations Community Based Screening to Improve Kidney Health and Prevent Dialysis (FINISHED) screen, triage, and treat program. Am J Kidney Dis. 2016;68(4):582-590. doi:10.1053/j.ajkd.2016.04.014 27257016
293 Pavkov ME, Hanson RL, Knowler WC, Sievers ML, Bennett PH, Nelson RG. Effect of intrauterine diabetes exposure on the incidence of end-stage renal disease in young adults with type 2 diabetes. Diabetes Care. 2010;33(11):2396-2398. doi:10.2337/dc10-0811 20693350
294 Laffel LM, Danne T, Klingensmith GJ, et al. Efficacy and safety of the SGLT2 inhibitor empagliflozin versus placebo and the DPP-4 inhibitor linagliptin versus placebo in young people with type 2 diabetes (DINAMO): a multicentre, randomised, double-blind, parallel group, phase 3 trial. Lancet Diabetes Endocrinol. 2023;11(3):169-181. doi:10.1016/S2213-8587(22)00387-4 36738751
295 Tamborlane WV, Laffel LM, Shehadeh N, et al. Efficacy and safety of dapagliflozin in children and young adults with type 2 diabetes: a prospective, multicentre, randomised, parallel group, phase 3 study. Lancet Diabetes Endocrinol. 2022;10(5):341-350. doi:10.1016/S2213-8587(22)00052-3 35378069
296 Bjornstad P, Laffel L, Tamborlane WV, et al. Acute effect of empagliflozin on fractional excretion of sodium and eGFR in youth with type 2 diabetes. Diabetes Care. 2018;41(8):e129-e130. doi:10.2337/dc18-0394 29941496
297 Perkovic V, Jardine MJ, Neal B, et al. Canagliflozin and renal outcomes in type 2 diabetes and nephropathy. N Engl J Med. 2019;380(24):2295-2306. doi:10.1056/NEJMoa1811744 30990260
298 Tamborlane WV, Barrientos-Pérez M, Fainberg U, et al. Liraglutide in children and adolescents with type 2 diabetes. N Engl J Med. 2019;381(7):637-646. doi:10.1056/NEJMoa1903822 31034184
299 Bjornstad P, Arslanian SA, Hannon TS, et al. Dulaglutide and glomerular hyperfiltration, proteinuria, and albuminuria in youth with type 2 diabetes: post hoc analysis of the AWARD-PEDS study. Diabetes Care. 2024;47(9):1617-1621. doi:10.2337/dc24-0322 38954432
300 Bakris GL, Agarwal R, Anker SD, et al. Effect of finerenone on chronic kidney disease outcomes in type 2 diabetes. N Engl J Med. 2020;383(23):2219-2229. doi:10.1056/NEJMoa2025845 33264825
301 Pop-Busui R, Boulton AJ, Feldman EL, et al. Diabetic Neuropathy: a position statement by the American Diabetes Association. Diabetes Care. 2017;40(1):136-154. doi:10.2337/dc16-2042 27999003
302 Albers JW, Pop-Busui R. Diabetic neuropathy: mechanisms, emerging treatments, and subtypes. Curr Neurol Neurosci Rep. 2014;14(8):473. doi:10.1007/s11910-014-0473-5 24954624
303 Feldman EL, Stevens MJ, Thomas PK, Brown MB, Canal N, Greene DA. A practical two-step quantitative clinical and electrophysiological assessment for the diagnosis and staging of diabetic neuropathy. Diabetes Care. 1994;17(11):1281-1289. doi:10.2337/diacare.17.11.1281 7821168
304 Herman WH, Pop-Busui R, Braffett BH, et al. Use of the Michigan Neuropathy Screening Instrument as a measure of distal symmetrical peripheral neuropathy in type 1 diabetes: results from the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications. Diabet Med. 2012;29(7):937-944. doi:10.1111/j.1464-5491.2012.03644.x 22417277
305 Jaiswal M, Divers J, Dabelea D, et al. Prevalence of and risk factors for diabetic peripheral neuropathy in youth with type 1 and type 2 diabetes: SEARCH for Diabetes in Youth study. Diabetes Care. 2017;40(9):1226-1232. doi:10.2337/dc17-0179 28674076
306 Olsen BS, Johannesen J, Sjølie AK, et al. Metabolic control and prevalence of microvascular complications in young Danish patients with type 1 diabetes mellitus. Danish Study Group of Diabetes in Childhood. Diabet Med. 1999;16(1):79-85. doi:10.1046/j.1464-5491.1999.00024.x 10229298
307 Walsh MG, Zgibor J, Borch-Johnsen K, Orchard TJ, DiaMond Investigators. A multinational comparison of complications assessment in type 1 diabetes: the DiaMond substudy of complications (DiaComp) level 2. Diabetes Care. 2004;27(7):1610-1617. doi:10.2337/diacare.27.7.1610 15220236
308 The effect of intensive diabetes therapy on the development and progression of neuropathy. The Diabetes Control and Complications Trial Research Group. Ann Intern Med. 1995;122(8):561-568. doi:10.7326/0003-4819-122-8-199504150-00001 7887548
309 Albers JW, Herman WH, Pop-Busui R, et al. Effort of prior intensive insulin therapy during the Diabetes Control and Complications Trial (DCCT) on peripheral neuropathy in type 1 diabetes during the Epidemiology of Diabetes Interventions and Complications (EDIC) Study. Diabetes Care. 2010;33(5):1090-1096. doi:10.2337/dc09-1941 20150297
310 TODAY Study Group. Risk factors for diabetic peripheral neuropathy in adolescents and young adults with type 2 diabetes: results from the TODAY study. Diabetes Care. 2021;45(5):1065-1072. doi:10.2337/dc21-1074 34716210
311 Vinik AI, Maser RE, Mitchell BD, Freeman R. Diabetic autonomic neuropathy. Diabetes Care. 2003;26(5):1553-1579. doi:10.2337/diacare.26.5.1553 12716821
312 Maser RE, Mitchell BD, Vinik AI, Freeman R. The association between cardiovascular autonomic neuropathy and mortality in individuals with diabetes: a meta-analysis. Diabetes Care. 2003;26(6):1895-1901. doi:10.2337/diacare.26.6.1895 12766130
313 Ziegler D, Zentai CP, Perz S, et al. Prediction of mortality using measures of cardiac autonomic dysfunction in the diabetic and nondiabetic population: the MONICA/KORA Augsburg Cohort Study. Diabetes Care. 2008;31(3):556-561. doi:10.2337/dc07-1615 18086873
314 Pop-Busui R, Evans GW, Gerstein HC, et al. Effects of cardiac autonomic dysfunction on mortality risk in the Action to Control Cardiovascular Risk in Diabetes (ACCORD) trial. Diabetes Care. 2010;33(7):1578-1584. doi:10.2337/dc10-0125 20215456
315 Pop-Busui R, Braffett BH, Zinman B, et al. Cardiovascular autonomic neuropathy and cardiovascular outcomes in the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) study. Diabetes Care. 2017;40(1):94-100. doi:10.2337/dc16-1397 27803120
316 Pop-Busui R, Backlund J-YC, Bebu I, et al. Utility of using electrocardiogram measures of heart rate variability as a measure of cardiovascular autonomic neuropathy in type 1 diabetes patients. J Diabetes Investig. 2022;13(1):125-133. doi:10.1111/jdi.13635 34309223
317 Tang M, Donaghue KC, Cho YH, Craig ME. Autonomic neuropathy in young people with type 1 diabetes: a systematic review. Pediatr Diabetes. 2013;14(4):239-248. doi:10.1111/pedi.12039 23627912
318 Cho YH, Craig ME, Jopling T, Chan A, Donaghue KC. Higher body mass index predicts cardiac autonomic dysfunction: a longitudinal study in adolescent type 1 diabetes. Pediatr Diabetes. 2018;19(4):794-800. doi:10.1111/pedi.12642 29383813
319 Metwalley KA, Hamed SA, Farghaly HS. Cardiac autonomic function in children with type 1 diabetes. Eur J Pediatr. 2018;177(6):805-813. doi:10.1007/s00431-018-3122-1 29500542
320 Jaiswal M, Urbina EM, Wadwa RP, et al. Reduced heart rate variability among youth with type 1 diabetes: the SEARCH CVD study. Diabetes Care. 2013;36(1):157-162. doi:10.2337/dc12-0463 22961570
321 Jaiswal M, Divers J, Urbina EM, et al. Cardiovascular autonomic neuropathy in adolescents and young adults with type 1 and type 2 diabetes: the SEARCH for Diabetes in Youth Cohort Study. Pediatr Diabetes. 2018;19(4):680-689. doi:10.1111/pedi.12633 29292558
322 Shah AS, Isom S, D’Agostino R, et al. Longitudinal changes in arterial stiffness and heart rate variability in youth-onset type 1 versus type 2 diabetes: the SEARCH for Diabetes in Youth study. Diabetes Care. 2022;45(7):1647-1656. doi:10.2337/dc21-2426 35667385
323 Sauder KA, Stafford JM, Mayer-Davis EJ, et al. Co-occurrence of early diabetes-related complications in adolescents and young adults with type 1 diabetes: an observational cohort study. Lancet Child Adolesc Health. 2019;3(1):35-43. doi:10.1016/S2352-4642(18)30309-2 30409691
324 Varley BJ, Gow ML, Cho YH, et al. Higher frequency of cardiovascular autonomic neuropathy in youth with type 2 compared to type 1 diabetes: role of cardiometabolic risk factors. Pediatr Diabetes. 2022;23(7):1073-1079. doi:10.1111/pedi.13393 35856852
325 Pop-Busui R, Low PA, Waberski BH, et al. Effects of prior intensive insulin therapy on cardiac autonomic nervous system function in type 1 diabetes mellitus: the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study (DCCT/EDIC). Circulation. 2009;119(22):2886-2893. doi:10.1161/CIRCULATIONAHA.108.837369 19470886
326 Shah AS, El Ghormli L, Vajravelu ME, et al. Heart rate variability and cardiac autonomic dysfunction: prevalence, risk factors, and relationship to arterial stiffness in the Treatment Options for Type 2 Diabetes in Adolescents and Youth (TODAY) study. Diabetes Care. 2019;42(11):2143-2150. doi:10.2337/dc19-0993 31501226
327 TODAY Study Group, Shah AS, El Ghormli L, et al. Longitudinal changes in vascular stiffness and heart rate variability among young adults with youth-onset type 2 diabetes: results from the follow-up observational treatment options for type 2 diabetes in adolescents and youth (TODAY) study. Acta Diabetol. 2022;59(2):197-205. doi:10.1007/s00592-021-01796-6 34542729
328 Shah AS, Jaiswal M, Dabelea D, et al. Cardiovascular risk and heart rate variability in young adults with type 2 diabetes and arterial stiffness: the SEARCH for Diabetes in Youth study. J Diabetes Complications. 2020;34(10):107676. doi:10.1016/j.jdiacomp.2020.107676 32713707
329 Kanwal F, Neuschwander-Tetri BA, Loomba R, Rinella ME. Metabolic dysfunction-associated steatotic liver disease: update and impact of new nomenclature on the American Association for the Study of Liver Diseases Practice Guidance on Nonalcoholic Fatty Liver Disease. Hepatology. 2024;79(5):1212-1219. doi:10.1097/HEP.0000000000000670 38445559
330 Castera L, Laouenan C, Vallet-Pichard A, et al. High prevalence of NASH and advanced fibrosis in type 2 diabetes: a prospective study of 330 outpatients undergoing liver biopsies for elevated ALT, using a low threshold. Diabetes Care. 2023;46(7):1354-1362. doi:10.2337/dc22-2048 37043830
331 Mantovani A, Petracca G, Beatrice G, Tilg H, Byrne CD, Targher G. Non-alcoholic fatty liver disease and risk of incident diabetes mellitus: an updated meta-analysis of 501 022 adult individuals. Gut. 2021;70(5):962-969. doi:10.1136/gutjnl-2020-322572 32938692
332 Putri RR, Casswall T, Danielsson P, Marcus C, Hagman E. Steatotic liver disease in pediatric obesity and increased risk for youth-onset type 2 diabetes. Diabetes Care. 2024;47(12):2196-2204. doi:10.2337/dc24-1236 39373987
333 Cusi K, Isaacs S, Barb D, et al. American Association of Clinical Endocrinology Clinical Practice Guideline for the Diagnosis and Management of Nonalcoholic Fatty Liver Disease in Primary Care and Endocrinology Clinical Settings: co-sponsored by the American Association for the Study of Liver Diseases (AASLD). Endocr Pract. 2022;28(5):528-562. doi:10.1016/j.eprac.2022.03.010 35569886
334 Tommerdahl KL, Baumgartner K, Schäfer M, et al. Impact of obesity on measures of cardiovascular and kidney health in youth with type 1 diabetes as compared with youth with type 2 diabetes. Diabetes Care. 2021;44(3):795-803. doi:10.2337/dc20-1879 33402367
335 Tas E, Bai S, Mak D, Diaz EC, Dranoff JA. Obesity, but not glycemic control, predicts liver steatosis in children with type 1 diabetes. J Diabetes Complications. 2022;36(12):108341. doi:10.1016/j.jdiacomp.2022.108341 36345110
336 Nadeau KJ, Regensteiner JG, Bauer TA, et al. Insulin resistance in adolescents with type 1 diabetes and its relationship to cardiovascular function. J Clin Endocrinol Metab. 2010;95(2):513-521. doi:10.1210/jc.2009-1756 19915016
337 Cree-Green M, Stuppy JJ, Thurston J, et al. Youth with type 1 diabetes have adipose, hepatic, and peripheral insulin resistance. J Clin Endocrinol Metab. 2018;103(10):3647-3657. doi:10.1210/jc.2018-00433 30020457
338 Nadeau KJ, Klingensmith G, Zeitler P. Type 2 diabetes in children is frequently associated with elevated alanine aminotransferase. J Pediatr Gastroenterol Nutr. 2005;41(1):94-98. doi:10.1097/01.mpg.0000164698.03164.e5 15990637
339 Hudson OD, Nunez M, Shaibi GQ. Ethnicity and elevated liver transaminases among newly diagnosed children with type 2 diabetes. BMC Pediatr. 2012;12:174. doi:10.1186/1471-2431-12-174 23134937
340 Bacha F, Cheng P, Gal RL, et al. Racial and ethnic disparities in comorbidities in youth with type 2 diabetes in the Pediatric Diabetes Consortium (PDC). Diabetes Care. 2021;44(10):2245-2251. doi:10.2337/dc21-0143 34475033
341 Bjornstad P, Chao LC, Cree-Green M, et al. Youth-onset type 2 diabetes mellitus: an urgent challenge. Nat Rev Nephrol. 2023;19(3):168-184. doi:10.1038/s41581-022-00645-1 36316388
342 Weinstock RS, Drews KL, Caprio S, et al. Metabolic syndrome is common and persistent in youth-onset type 2 diabetes: results from the TODAY clinical trial. Obesity (Silver Spring). 2015;23(7):1357-1361. doi:10.1002/oby.21120 26047470
343 Cree-Green M, Wiromrat P, Stuppy JJ, et al. Youth with type 2 diabetes have hepatic, peripheral, and adipose insulin resistance. Am J Physiol Endocrinol Metab. 2019;316(2):E186-E195. doi:10.1152/ajpendo.00258.2018 30562061
344 ClinicalTrials.gov. Surgical or medical treatment (ST2OMP). National Library of Medicine. Updated February 12, 2025. Accessed February 26, 2025. https://clinicaltrials.gov/study/NCT04128995.
345 Shah AS, Xanthakos S, Trout AT, et al. Liver health in adolescents with youth-onset type 2 diabetes. Diabetes. 2024;73(Suppl 1):149-OR. doi:10.2337/db24-149-OR
346 Wittmeier KD, Wicklow BA, MacIntosh AC, et al. Hepatic steatosis and low cardiorespiratory fitness in youth with type 2 diabetes. Obesity (Silver Spring). 2012;20(5):1034-1040. doi:10.1038/oby.2011.379 22222927
347 Amed S, Hamilton JK, Sellers EAC, et al. Differing clinical features in Aboriginal vs. non-Aboriginal children presenting with type 2 diabetes. Pediatr Diabetes. 2012;13(6):470-475. doi:10.1111/j.1399-5448.2012.00859.x 22369184
348 Hu C, Cioana M, Saini A, et al. The prevalence of non-alcoholic fatty liver disease in pediatric type 2 diabetes: a systematic review and meta-analysis. Front Adolesc Med. 2024;2(1303375)doi:10.3389/fradm.2024.1303375
349 Nicklas TA, von Duvillard SP, Berenson GS. Tracking of serum lipids and lipoproteins from childhood to dyslipidemia in adults: the Bogalusa Heart Study. Int J Sports Med. 2002;23(Suppl 1):S39-S43. doi:10.1055/s-2002-28460 12012261
350 Bao W, Srinivasan SR, Wattigney WA, Berenson GS. Persistence of multiple cardiovascular risk clustering related to syndrome X from childhood to young adulthood. The Bogalusa Heart Study. Arch Intern Med. 1994;154(16):1842-1847. doi:10.1001/archinte.1994.00420160079011 8053753
351 Frontini MG, Srinivasan SR, Xu J, Tang R, Bond MG, Berenson GS. Usefulness of childhood non-high density lipoprotein cholesterol levels versus other lipoprotein measures in predicting adult subclinical atherosclerosis: the Bogalusa Heart Study. Pediatrics. 2008;121(5):924-929. doi:10.1542/peds.2007-1472 18450895
352 Li S, Chen W, Srinivasan SR, Berenson GS. Childhood blood pressure as a predictor of arterial stiffness in young adults: the Bogalusa Heart Study. Hypertension. 2004;43(3):541-546. doi:10.1161/01.HYP.0000115922.98155.23 14744922
353 Freedman DS, Dietz WH, Tang R, et al. The relation of obesity throughout life to carotid intima-media thickness in adulthood: the Bogalusa Heart Study. Int J Obes Relat Metab Disord. 2004;28(1):159-166. doi:10.1038/sj.ijo.0802515 14581934
354 Preis SR, Pencina MJ, Hwang SJ, et al. Trends in cardiovascular disease risk factors in individuals with and without diabetes mellitus in the Framingham Heart Study. Circulation. 2009;120(3):212-220. doi:10.1161/CIRCULATIONAHA.108.846519 19581493
355 TODAY Study Group, Shah RD, Braffett BH, et al. Cardiovascular risk factor progression in adolescents and young adults with youth-onset type 2 diabetes. J Diabetes Complications. 2022;36(3):108123. doi:10.1016/j.jdiacomp.2021.108123 35123868
356 Kim G, Divers J, Fino NF, et al. Trends in prevalence of cardiovascular risk factors from 2002 to 2012 among youth early in the course of type 1 and type 2 diabetes. The SEARCH for Diabetes in Youth Study. Pediatr Diabetes. 2019;20(6):693-701. doi:10.1111/pedi.12846 30903717
357 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA. 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med. 2008;359(15):1577-1589. doi:10.1056/NEJMoa0806470 18784090
358 Stratton IM, Adler AI, Neil HA, et al. Association of glycaemia with macrovascular and microvascular complications of type 2 diabetes (UKPDS 35): prospective observational study. BMJ. 2000;321(7258):405-412. doi:10.1136/bmj.321.7258.405 10938048
359 Nathan DM, Cleary PA, Backlund J-YC, et al. Intensive diabetes treatment and cardiovascular disease in patients with type 1 diabetes. N Engl J Med. 2005;353(25):2643-2653. doi:10.1056/NEJMoa052187 16371630
360 Eeg-Olofsson K, Cederholm J, Nilsson PM, et al. Glycemic control and cardiovascular disease in 7,454 patients with type 1 diabetes: an observational study from the Swedish National Diabetes Register (NDR). Diabetes Care. 2010;33(7):1640-1646. doi:10.2337/dc10-0398 20424222
361 Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) Research Group. Risk factors for cardiovascular disease in type 1 diabetes. Diabetes. 2016;65(5):1370-1379. doi:10.2337/db15-1517 26895792
362 Stettler C, Allemann S, Juni P, et al. Glycemic control and macrovascular disease in types 1 and 2 diabetes mellitus: meta-analysis of randomized trials. Am Heart J. 2006;152(1):27-38. doi:10.1016/j.ahj.2005.09.015 16824829
363 Chalew SA, Gomez R, Butler A, et al. Predictors of glycemic control in children with type 1 diabetes: the importance of race. J Diabetes Complications. 2000;14(2):71-77. doi:10.1016/s1056-8727(00)00072-6 10959068
364 Gallegos-Macias AR, Macias SR, Kaufman E, Skipper B, Kalishman N. Relationship between glycemic control, ethnicity and socioeconomic status in Hispanic and white non-Hispanic youths with type 1 diabetes mellitus. Pediatr Diabetes. 2003;4(1):19-23. doi:10.1034/j.1399-5448.2003.00020.x 14655519
365 Moreland EC, Tovar A, Zuehlke JB, Butler DA, Milaszewski K, Laffel LM. The impact of physiological, therapeutic and psychosocial variables on glycemic control in youth with type 1 diabetes mellitus. J Pediatr Endocrinol Metab. 2004;17(11):1533-1544. doi:10.1515/jpem.2004.17.11.1533 15570991
366 Anderson B, Ho J, Brackett J, Finkelstein D, Laffel L. Parental involvement in diabetes management tasks: relationships to blood glucose monitoring adherence and metabolic control in young adolescents with insulin-dependent diabetes mellitus. J Pediatr. 1997;130(2):257-265. doi:10.1016/s0022-3476(97)70352-4 9042129
367 Rothman RL, Mulvaney S, Elasy TA, et al. Self-management behaviors, racial disparities, and glycemic control among adolescents with type 2 diabetes. Pediatrics. 2008;121(4):e912-e919. doi:10.1542/peds.2007-1484 18381520
368 Chernausek SD, Arslanian S, Caprio S, et al. Relationship between parental diabetes and presentation of metabolic and glycemic function in youth with type 2 diabetes: baseline findings from the TODAY trial. Diabetes Care. 2016;39(1):110-117. doi:10.2337/dc15-1557 26577415
369 Carino M, Elia Y, Sellers E, et al. Comparison of clinical and social characteristics of Canadian youth living with type 1 and type 2 diabetes. Can J Diabetes. 2021;45(5):428-435. doi:10.1016/j.jcjd.2021.01.008 33714663
370 Kahkoska AR, Shay CM, Crandell J, et al. Association of race and ethnicity with glycemic control and hemoglobin A(1c) levels in youth with type 1 diabetes. JAMA Netw Open. 2018;1(5):e181851. doi:10.1001/jamanetworkopen.2018.1851 30370425
371 Liese AD, Reboussin BA, Kahkoska AR, et al. Inequalities in glycemic control in youth with type 1 diabetes over time: intersectionality between socioeconomic position and race and ethnicity. Ann Behav Med. 2022;56(5):461-471. doi:10.1093/abm/kaab086 34570884
372 Petitti DB, Klingensmith GJ, Bell RA, et al. Glycemic control in youth with diabetes: the SEARCH for Diabetes in Youth study. J Pediatr. 2009;155(5):668-672 e1-3. doi:10.1016/j.jpeds.2009.05.025
373 Albers JJ, Marcovina SM, Imperatore G, et al. Prevalence and determinants of elevated apolipoprotein B and dense low-density lipoprotein in youths with type 1 and type 2 diabetes. J Clin Endocrinol Metab. 2008;93(3):735-742. doi:10.1210/jc.2007-2176 18089692
374 Svoren BM, Volkening LK, Butler DA, Moreland EC, Anderson BJ, Laffel LMB. Temporal trends in the treatment of pediatric type 1 diabetes and impact on acute outcomes. J Pediatr. 2007;150(3):279-285. doi:10.1016/j.jpeds.2006.12.009 17307546
375 Margeirsdottir HD, Larsen JR, Kummernes SJ, Brunborg C, Dahl-Jørgensen K. The establishment of a new national network leads to quality improvement in childhood diabetes: implementation of the ISPAD Guidelines. Pediatr Diabetes. 2010;11(2):88-95. doi:10.1111/j.1399-5448.2009.00542.x 19552727
376 Bulsara MK, Holman CDJ, Davis EA, Jones TW. The impact of a decade of changing treatment on rates of severe hypoglycemia in a population-based cohort of children with type 1 diabetes. Diabetes Care. 2004;27(10):2293-2298. doi:10.2337/diacare.27.10.2293 15451890
377 Malik FS, Sauder KA, Isom S, et al. Trends in glycemic control among youth and young adults with diabetes: the SEARCH for Diabetes in Youth study. Diabetes Care. 2022;45(2):285-294. doi:10.2337/dc21-0507 34995346
378 Redondo MJ, Libman I, Cheng P, et al. Racial/ethnic minority youth with recent-onset type 1 diabetes have poor prognostic factors. Diabetes Care. 2018;41(5):1017-1024. doi:10.2337/dc17-2335 29496742
379 de Bock M, Agwu JC, Deabreu M, et al. International Society for Pediatric and Adolescent Diabetes Clinical Practice Consensus Guidelines 2024: Glycemic Targets. Horm Res Paediatr. 2024;97(6):546-554. doi:10.1159/000543266 39701064
380 Gerhardsson P, Schwandt A, Witsch M, et al. The SWEET project 10-year benchmarking in 19 countries worldwide is associated with improved HbA1c and increased use of diabetes technology in youth with type 1 diabetes. Diabetes Technol Ther. 2021;23(7):491-499. doi:10.1089/dia.2020.0618 33566729
381 Royal College of Paediatrics and Child Health. National Paediatric Diabetes Audit Annual Report 2019–20: Care Processes and Outcomes. 2021. Updated 2021. Accessed October 19, 2021. https://www.rcpch.ac.uk/resources/npda-annual-reports#downloadBox
382 Royal College of Paediatrics and Child Health. National Paediatric Diabetes Audit Annual Report 2022–23: Care Processes and Outcomes. 2025. Accessed February 22, 2025. https://www.rcpch.ac.uk/resources/npda-annual-reports
383 TODAY Study Group. Effects of metformin, metformin plus rosiglitazone, and metformin plus lifestyle on insulin sensitivity and β-cell function in TODAY. Diabetes Care. 2013;36(6):1749-1757. doi:10.2337/dc12-2393 23704674
384 RISE Consortium. Impact of insulin and metformin versus metformin alone on β-cell function in youth with impaired glucose tolerance or recently diagnosed type 2 diabetes. Diabetes Care. 2018;41(8):1717-1725. doi:10.2337/dc18-0787 29941500
385 Nambam B, Silverstein J, Cheng P, et al. A cross-sectional view of the current state of treatment of youth with type 2 diabetes in the USA: enrollment data from the Pediatric Diabetes Consortium Type 2 Diabetes Registry. Pediatr Diabetes. 2017;18(3):222-229. doi:10.1111/pedi.12377 26970319
386 TODAY Study Group. Long-term outcomes among young adults with type 2 diabetes based on durability of glycemic control: results from the TODAY cohort study. Diabetes Care. 2022;45(11):2689-2697. doi:10.2337/dc22-0784 36190810
387 Sam S, Edelstein SL, Arslanian SA, et al. Baseline predictors of glycemic worsening in youth and adults with impaired glucose tolerance or recently diagnosed type 2 diabetes in the Restoring Insulin Secretion (RISE) study. Diabetes Care. 2021;44(9):1938-1947. doi:10.2337/dc21-0027 34131048
388 Flynn JT, Kaelber DC, Baker-Smith CM, et al. Clinical Practice Guideline for Screening and Management of High Blood Pressure in Children and Adolescents. Pediatrics. 2017;140(3):e20171904. doi:10.1542/peds.2017-1904 28827377
389 Rodriguez BL, Dabelea D, Liese AD, et al. Prevalence and correlates of elevated blood pressure in youth with diabetes mellitus: the SEARCH for Diabetes in Youth study. J Pediatr. 2010;157(2):245-251 e1. doi:10.1016/j.jpeds.2010.02.021 20394942
390 Sellers EA, Yung G, Dean HJ. Dyslipidemia and other cardiovascular risk factors in a Canadian First Nation pediatric population with type 2 diabetes mellitus. Pediatr Diabetes. 2007;8(6):384-390. doi:10.1111/j.1399-5448.2007.00284.x 18036065
391 Koebnick C, Imperatore G, Jensen ET, et al. Progression to hypertension in youth and young adults with type 1 or type 2 diabetes: the SEARCH for Diabetes in Youth Study. J Clin Hypertens (Greenwich). 2020;22(5):888-896. doi:10.1111/jch.13849 32297456
392 James S, Perry L, Lowe J, et al. Blood pressure in adolescents and young adults with type 1 diabetes: data from the Australasian Diabetes Data Network registry. Acta Diabetol. 2023;60(6):797-803. doi:10.1007/s00592-023-02057-4 36920547
393 Schwab KO, Doerfer J, Hecker W, et al. Spectrum and prevalence of atherogenic risk factors in 27,358 children, adolescents, and young adults with type 1 diabetes: cross-sectional data from the German diabetes documentation and quality management system (DPV). Diabetes Care. 2006;29(2):218-225. doi:10.2337/diacare.29.02.06.dc05-0724 16443863
394 Tracy RE, Newman WP, 3rd, Wattigney WA, Berenson GS. Risk factors and atherosclerosis in youth autopsy findings of the Bogalusa Heart Study. Am J Med Sci. 1995;310(Suppl 1):S37-S41. doi:10.1097/00000441-199512000-00007 7503122
395 American Diabetes Association. Management of dyslipidemia in children and adolescents with diabetes. Diabetes Care. 2003;26(7):2194-2197. doi:.10.2337/diacare.26.7.2194 12832334
396 Maahs DM, Maniatis AK, Nadeau K, Wadwa RP, McFann K, Klingensmith GJ. Total cholesterol and high-density lipoprotein levels in pediatric subjects with type 1 diabetes mellitus. J Pediatr. 2005;147(4):544-546. doi:10.1016/j.jpeds.2005.04.068 16227045
397 Kershnar AK, Daniels SR, Imperatore G, et al. Lipid abnormalities are prevalent in youth with type 1 and type 2 diabetes: the SEARCH for Diabetes in Youth Study. J Pediatr. 2006;149(3):314-319. doi:10.1016/j.jpeds.2006.04.065 16939739
398 Petitti DB, Imperatore G, Palla SL, et al. Serum lipids and glucose control: the SEARCH for Diabetes in Youth study. Arch Pediatr Adolesc Med. 2007;161(2):159-165. doi:10.1001/archpedi.161.2.159 17283301
399 Guy J, Ogden L, Wadwa RP, et al. Lipid and lipoprotein profiles in youth with and without type 1 diabetes: the SEARCH for Diabetes in Youth Case-Control Study. Diabetes Care. 2009;32(3):416-420. doi:10.2337/dc08-1775 19092167
400 Maahs DM, Dabelea D, D’Agostino RB, Jr., et al. Glucose control predicts 2-year change in lipid profile in youth with type 1 diabetes. J Pediatr. 2013;162(1):101-107.e1. doi:10.1016/j.jpeds.2012.06.006 22795314
401 Shah AS, Maahs DM, Stafford JM, et al. Predictors of dyslipidemia over time in youth with type 1 diabetes: for the SEARCH for Diabetes in Youth study. Diabetes Care. 2017;40(4):607-613. doi:10.2337/dc16-2193 28126715
402 Maahs DM, Wadwa RP, McFann K, et al. Longitudinal lipid screening and use of lipid-lowering medications in pediatric type 1 diabetes. J Pediatr. 2007;150(2):146-50, 150 e1-2. doi:10.1016/j.jpeds.2006.10.054
403 Fortmeier-Saucier L, Savrin C, Heinzer M, Hudak C. BMI and lipid levels in Mexican American children diagnosed with type 2 diabetes. Worldviews Evid Based Nurs. 2008;5(3):142-147. doi:10.1111/j.1741-6787.2008.00122.x 19076913
404 Brady RP, Shah AS, Jensen ET, et al. Glycemic control is associated with dyslipidemia over time in youth with type 2 diabetes: the SEARCH for diabetes in youth study. Pediatr Diabetes. 2021;22(7):951-959. doi:10.1111/pedi.13253 34363298
405 TODAY Study Group. Lipid and inflammatory cardiovascular risk worsens over 3 years in youth with type 2 diabetes: the TODAY clinical trial. Diabetes Care. 2013;36(6):1758-1764. doi:10.2337/dc12-2388 23704675
406 Mayer-Davis EJ, Ma B, Lawson A, et al. Cardiovascular disease risk factors in youth with type 1 and type 2 diabetes: implications of a factor analysis of clustering. Metab Syndr Relat Disord. 2009;7(2):89-95. doi:10.1089/met.2008.0046 18847385
407 Libman IM, Pietropaolo M, Arslanian SA, LaPorte RE, Becker DJ. Changing prevalence of overweight children and adolescents at onset of insulin-treated diabetes. Diabetes Care. 2003;26(10):2871-2875. doi:10.2337/diacare.26.10.2871 14514594
408 Maahs DM, Nadeau K, Snell-Bergeon JK, et al. Association of insulin sensitivity to lipids across the lifespan in people with type 1 diabetes. Diabet Med. 2011;28(2):148-155. doi:10.1111/j.1464-5491.2010.03143.x 21219421
409 Pinhas-Hamiel O, Dolan LM, Daniels SR, Standiford D, Khoury PR, Zeitler P. Increased incidence of non-insulin-dependent diabetes mellitus among adolescents. J Pediatr. 1996;128(5 Pt 1):608-615. doi:10.1016/s0022-3476(96)80124-7 8627431
410 Cioana M, Deng J, Nadarajah A, et al. The prevalence of obesity among children with type 2 diabetes: a systematic review and meta-analysis. JAMA Netw Open. 2022;5(12):e2247186. doi:10.1001/jamanetworkopen.2022.47186 36520430
411 Gungor N, Bacha F, Saad R, Janosky J, Arslanian S. Youth type 2 diabetes: insulin resistance, β-cell failure, or both? Diabetes Care. 2005;28(3):638-644. doi:10.2337/diacare.28.3.638 15735201
412 RISE Consortium. Metabolic contrasts between youth and adults with impaired glucose tolerance or recently diagnosed type 2 diabetes. I. Observations using the hyperglycemic clamp. Diabetes Care. 2018;41(8):1696-1706. doi:10.2337/dc18-0244 29941497
413 RISE Consortium. Metabolic contrasts between youth and adults with impaired glucose tolerance or recently diagnosed type 2 diabetes. II. Observations using the oral glucose tolerance test. Diabetes Care. 2018;41(8):1707-1716. doi:10.2337/dc18-0243 29941498
414 RISE Consortium. Obesity and insulin sensitivity effects on cardiovascular risk factors: comparisons of obese dysglycemic youth and adults. Pediatr Diabetes. 2019;20(7):849-860. doi:10.1111/pedi.12883 31301210
415 Brooks B, Molyneaux L, Yue DK. Augmentation of central arterial pressure in type 1 diabetes. Diabetes Care. 1999;22(10):1722-1727. doi:10.2337/diacare.22.10.1722 10526742
416 Schram MT, Chaturvedi N, Fuller JH, Stehouwer CD, EURODIAB Prospective Complications Study Group. Pulse pressure is associated with age and cardiovascular disease in type 1 diabetes: the EURODIAB Prospective Complications Study. J Hypertens. 2003;21(11):2035-2044. doi:10.1097/00004872-200311000-00012 14597846
417 Blacher J, Asmar R, Djane S, London GM, Safar ME. Aortic pulse wave velocity as a marker of cardiovascular risk in hypertensive patients. Hypertension. 1999;33(5):1111-1117. doi:10.1161/01.hyp.33.5.1111 10334796
418 Cruickshank K, Riste L, Anderson SG, Wright JS, Dunn G, Gosling RG. Aortic pulse-wave velocity and its relationship to mortality in diabetes and glucose intolerance: an integrated index of vascular function? Circulation. 2002;106(16):2085-2090. doi:10.1161/01.cir.0000033824.02722.f7 12379578
419 Kim JM, Kim SS, Kim IJ, et al. Arterial stiffness is an independent predictor for risk of mortality in patients with type 2 diabetes mellitus: the REBOUND study. Cardiovasc Diabetol. 2020;19(1):143. doi:10.1186/s12933-020-01120-6 32962704
420 Haller MJ, Samyn M, Nichols WW, et al. Radial artery tonometry demonstrates arterial stiffness in children with type 1 diabetes. Diabetes Care. 2004;27(12):2911-2917. doi:10.2337/diacare.27.12.2911 15562206
421 Urbina EM, Isom S, Bell RA, et al. Burden of cardiovascular risk factors over time and arterial stiffness in youth with type 1 diabetes mellitus: the SEARCH for Diabetes in Youth study. J Am Heart Assoc. 2019;8(13):e010150. doi:10.1161/JAHA.118.010150 31213111
422 Stakos DA, Schuster DP, Sparks EA, Wooley CF, Osei K, Boudoulas H. Cardiovascular effects of type 1 diabetes mellitus in children. Angiology. 2005;56(3):311-317. doi:10.1177/000331970505600311 15889199
423 Podgórski M, Szatko K, Stańczyk M, et al. Two-dimensional speckle tracking versus applanation tonometry in evaluation of subclinical atherosclerosis in children with type 1 diabetes mellitus. Med Sci Monit. 2019;25:7289-7294. doi:10.12659/MSM.916466 31562737
424 Georeli E, Stamati A, Dimitriadou M, et al. Assessment of arterial stiffness in paediatric patients with type 1 diabetes mellitus. J Diabetes Complications. 2024;38(8):108782. doi:10.1016/j.jdiacomp.2024.108782 38917602
425 Christoforidis A, Georeli I, Dimitriadou M, Galli-Tsinopoulou A, Stabouli S. Arterial stiffness indices in children and adolescents with type 1 diabetes mellitus: a meta-analysis. Diabetes Metab Res Rev. 2022;38(6):e3555. doi:10.1002/dmrr.3555 35675380
426 Giannopoulou EZ, Doundoulakis I, Antza C, et al. Subclinical arterial damage in children and adolescents with type 1 diabetes: a systematic review and meta-analysis. Pediatr Diabetes. 2019;20(6):668-677. doi:10.1111/pedi.12874 31173658
427 Dabelea D, Talton JW, D’Agostino R, Jr., et al. Cardiovascular risk factors are associated with increased arterial stiffness in youth with type 1 diabetes: the SEARCH CVD study. Diabetes Care. 2013;36(12):3938-3943. doi:10.2337/dc13-0851 24101697
428 Shah AS, Wadwa RP, Dabelea D, et al. Arterial stiffness in adolescents and young adults with and without type 1 diabetes: the SEARCH CVD study. Pediatr Diabetes. 2015;16(5):367-374. doi:10.1111/pedi.12279 25912292
429 Sauder KA, Glueck DH, Harrall KK, et al. Exploring racial and ethnic differences in arterial stiffness among youth and young adults with type 1 diabetes. J Am Heart Assoc. 2023;12(7):e028529. doi:10.1161/JAHA.122.028529 36994741
430 Shah AS, El Ghormli L, Gidding SS, et al. Prevalence of arterial stiffness in adolescents with type 2 diabetes in the TODAY cohort: relationships to glycemic control and other risk factors. J Diabetes Complications. 2018;32(8):740-745. doi:10.1016/j.jdiacomp.2018.05.013 29936086
431 Ferreira MT, Leite NC, Cardoso CR, Salles GF. Correlates of aortic stiffness progression in patients with type 2 diabetes: importance of glycemic control: the Rio de Janeiro Type 2 Diabetes Cohort Study. Diabetes Care. 2015;38(5):897-904. doi:10.2337/dc14-2791 25678104
432 Moh MC, Sum CF, Tavintharan S, et al. Baseline predictors of aortic stiffness progression among multi-ethnic Asians with type 2 diabetes. Atherosclerosis. 2017;260:102-109. doi:10.1016/j.atherosclerosis.2017.01.031 28376407
433 Ryder JR, Northrop E, Rudser KD, et al. Accelerated early vascular aging among adolescents with obesity and/or type 2 diabetes mellitus. J Am Heart Assoc. 2020;9(10):e014891. doi:10.1161/JAHA.119.014891 32370578
434 Shah AS, Khoury PR, Dolan LM, et al. The effects of obesity and type 2 diabetes mellitus on cardiac structure and function in adolescents and young adults. Diabetologia. 2011;54(4):722-730. doi:10.1007/s00125-010-1974-7 21085926
435 Shah AS, Gidding SS, El Ghormli L, et al. Relationship between arterial stiffness and subsequent cardiac structure and function in young adults with youth-onset type 2 diabetes: results from the TODAY study. J Am Soc Echocardiogr. 2022;35(6):620-628.e4. doi:10.1016/j.echo.2022.02.001 35149207
436 Urbina EM, Isom S, Dabelea D, et al. Association of elevated arterial stiffness with cardiac target organ damage and cardiac autonomic neuropathy in young adults with diabetes: the SEARCH for Diabetes in Youth study. Diabetes Care. 2023;46(4):786-793. doi:10.2337/dc22-1703 36730642
437 Singh TP, Groehn H, Kazmers A. Vascular function and carotid intimal-medial thickness in children with insulin-dependent diabetes mellitus. J Am Coll Cardiol. 2003;41(4):661-665. doi:10.1016/s0735-1097(02)02894-2 12598080
438 Krantz JS, Mack WJ, Hodis HN, Liu C-R, Liu C-H, Kaufman FR. Early onset of subclinical atherosclerosis in young persons with type 1 diabetes. J Pediatr. 2004;145(4):452-457. doi:10.1016/j.jpeds.2004.06.042 15480366
439 Urbina EM, Dabelea D, D’Agostino RB, Jr., et al. Effect of type 1 diabetes on carotid structure and function in adolescents and young adults: the SEARCH CVD study. Diabetes Care. 2013;36(9):2597-2599. doi:10.2337/dc12-2024 23564920
440 Shah AS, Dabelea D, Fino NF, et al. Predictors of increased carotid intima-media thickness in youth with type 1 diabetes: the SEARCH CVD Study. Diabetes Care. 2016;39(3):418-425. doi:10.2337/dc15-1963 26721813
441 Glackin S, Islam N, Henderson AM, et al. Ambulatory blood pressure and carotid intima media thickness in children with type 1 diabetes. Pediatr Diabetes. 2020;21(2):358-365. doi:10.1111/pedi.12960 31825119
442 Lee SH, Kim JH, Kang MJ, Lee YA, Won Yang S, Shin CH. Implications of nocturnal hypertension in children and adolescents with type 1 diabetes. Diabetes Care. 2011;34(10):2180-2185. doi:10.2337/dc11-0830 21911774
443 Dalla Pozza R, Beyerlein A, Thilmany C, et al. The effect of cardiovascular risk factors on the longitudinal evolution of the carotid intima medial thickness in children with type 1 diabetes mellitus. Cardiovasc Diabetol. 2011;10:53. doi:10.1186/1475-2840-10-53 21679428
444 Nathan DM, Lachin J, Cleary P, et al. Intensive diabetes therapy and carotid intima-media thickness in type 1 diabetes mellitus. N Engl J Med. 2003;348(23):2294-2303. doi:10.1056/NEJMoa022314 12788993
445 Polak JF, Backlund J-YC, Cleary PA, et al. Progression of carotid artery intima-media thickness during 12 years in the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) study. Diabetes. 2011;60(2):607-613. doi:10.2337/db10-0296 21270271
446 Rabago Rodriguez R, Gómez-Díaz RA, Tanus Haj J, et al. Carotid intima-media thickness in pediatric type 1 diabetic patients. Diabetes Care. 2007;30(10):2599-2602. doi:10.2337/dc07-0922 17644614
447 Urbina EM, Kimball TR, McCoy CE, Khoury PR, Daniels SR, Dolan LM. Youth with obesity and obesity-related type 2 diabetes mellitus demonstrate abnormalities in carotid structure and function. Circulation. 2009;119(22):2913-2919. doi:10.1161/CIRCULATIONAHA.108.830380 19470890
448 Shah AS, Dolan LM, Kimball TR, et al. Influence of duration of diabetes, glycemic control, and traditional cardiovascular risk factors on early atherosclerotic vascular changes in adolescents and young adults with type 2 diabetes mellitus. J Clin Endocrinol Metab. 2009;94(10):3740-3745. doi:10.1210/jc.2008-2039 19723759
449 Shah AS, Urbina EM, Khoury PR, Kimball TR, Dolan LM. Lipids and lipoprotein ratios: contribution to carotid intima media thickness in adolescents and young adults with type 2 diabetes mellitus. J Clin Lipidol. 2013;7(5):441-445. doi:10.1016/j.jacl.2013.05.002 24079285
450 Guillemette L, Dart A, Wicklow B, et al. Cardiac structure and function in youth with type 2 diabetes in the iCARE cohort study: cross-sectional associations with prenatal exposure to diabetes and metabolomic profiles. Pediatr Diabetes. 2020;21(2):233-242. doi:10.1111/pedi.12954 31802590
451 Sellers EAC, Dart AB, McGavock J, Wicklow BA. Cardiovascular comorbidity associated with albuminuria in youth-onset type 2 diabetes: analyses from the iCARE study. Can J Diabetes. 2021;45(5):458-465. doi:10.1016/j.jcjd.2021.04.002 34045147
452 Naylor LH, Green DJ, Jones TW, et al. Endothelial function and carotid intima-medial thickness in adolescents with type 2 diabetes mellitus. J Pediatr. 2011;159(6):971-974. doi:10.1016/j.jpeds.2011.05.019 21722916
453 Kotb NA, Gaber R, Salama M, Nagy HM, Elhendy A. Clinical and biochemical predictors of increased carotid intima-media thickness in overweight and obese adolescents with type 2 diabetes. Diab Vasc Dis Res. 2012;9(1):35-41. doi:10.1177/1479164111421804 21985955
454 Starkman HS, Cable G, Hala V, Hecht H, Donnelly CM. Delineation of prevalence and risk factors for early coronary artery disease by electron beam computed tomography in young adults with type 1 diabetes. Diabetes Care. 2003;26(2):433-436. doi:10.2337/diacare.26.2.433 12547875
455 Costacou T, Edmundowicz D, Prince C, Conway B, Orchard TJ. Progression of coronary artery calcium in type 1 diabetes mellitus. Am J Cardiol. 2007;100(10):1543-1547. doi:10.1016/j.amjcard.2007.06.050 17996516
456 Guo J, Nunley KA, Costacou T, et al. Greater progression of coronary artery calcification is associated with clinically relevant cognitive impairment in type 1 diabetes. Atherosclerosis. 2019;280:58-65. doi:10.1016/j.atherosclerosis.2018.11.003 30471556
457 Dabelea D, Kinney G, Snell-Bergeon JK, et al. Effect of type 1 diabetes on the gender difference in coronary artery calcification: a role for insulin resistance? The Coronary Artery Calcification in Type 1 Diabetes (CACTI) Study. Diabetes. 2003;52(11):2833-2839. doi:10.2337/diabetes.52.11.2833 14578303
458 Snell-Bergeon JK, Hokanson JE, Jensen L, et al. Progression of coronary artery calcification in type 1 diabetes: the importance of glycemic control. Diabetes Care. 2003;26(10):2923-2928. doi:10.2337/diacare.26.10.2923 14514603
459 Rodrigues TC, Ehrlich J, Hunter CM, Kinney GL, Rewers M, Snell-Bergeon JK. Reduced heart rate variability predicts progression of coronary artery calcification in adults with type 1 diabetes and controls without diabetes. Diabetes Technol Ther. 2010;12(12):963-969. doi:10.1089/dia.2010.0070 21128843
460 Cleary PA, Orchard TJ, Genuth S, et al. The effect of intensive glycemic treatment on coronary artery calcification in type 1 diabetic participants of the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) Study. Diabetes. 2006;55(12):3556-3565. doi:10.2337/db06-0653 17130504
461 Lawrence JM, Reynolds K, Saydah SH, et al. Demographic correlates of short-term mortality among youth and young adults with youth-onset diabetes diagnosed from 2002 to 2015: the SEARCH for Diabetes in Youth Study. Diabetes Care. 2021;44(12):2691-2698. doi:10.2337/dc21-0728 34607833
462 Burnet DL, Cooper AJ, Drum ML, Lipton RB. Risk factors for mortality in a diverse cohort of patients with childhood-onset diabetes in Chicago. Diabetes Care. 2007;30(10):2559-2563. doi:10.2337/dc07-0216 17644621
463 Saydah S, Imperatore G, Cheng Y, Geiss LS, Albright A. Disparities in diabetes deaths among children and adolescents—United States, 2000–2014. MMWR Morb Mortal Wkly Rep. 2017;66(19):502-505. doi:10.15585/mmwr.mm6619a4 28520705
464 Jaser SS, Roddy MK, Beam AB. Psychosocial and behavioral health among youth and adults with diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2025. https://www.ncbi.nlm.nih.gov/books/NBK612770/
465 Waitzfelder B, Pihoker C, Klingensmith G, et al. Adherence to guidelines for youths with diabetes mellitus. Pediatrics. 2011;128(3):531-538. doi:10.1542/peds.2010-3641 21859914
466 Wood JR, Miller KM, Maahs DM, et al. Most youth with type 1 diabetes in the T1D Exchange Clinic Registry do not meet American Diabetes Association or International Society for Pediatric and Adolescent Diabetes clinical guidelines. Diabetes Care. 2013;36(7):2035-2037. doi:10.2337/dc12-1959 23340893
467 Canedo JR, Miller ST, Schlundt D, Fadden MK, Sanderson M. Racial/ethnic disparities in diabetes quality of care: the role of healthcare access and socioeconomic status. J Racial Ethn Health Disparities. 2018;5(1):7-14. doi:10.1007/s40615-016-0335-8 28078660
468 Christakis DA, Feudtner C, Pihoker C, Connell FA. Continuity and quality of care for children with diabetes who are covered by Medicaid. Ambul Pediatr. 2001;1(2):99-103. doi:10.1367/1539-4409(2001)001<0099:caqocf>2.0.co;2 11888380
469 Pihoker C, Braffett BH, Songer TJ, et al. Diabetes care barriers, use, and health outcomes in younger adults with type 1 and type 2 diabetes. JAMA Netw Open. 2023;6(5):e2312147. doi:10.1001/jamanetworkopen.2023.12147 37145592
470 Malik FS, Stafford JM, Reboussin BA, et al. Receipt of recommended complications and comorbidities screening in youth and young adults with type 1 diabetes: associations with metabolic status and satisfaction with care. Pediatr Diabetes. 2020;21(2):349-357. doi:10.1111/pedi.12948 31797506
471 Hwang JH, Ali MK, Huang ES. Quality of care in adults with diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2025. https://www.ncbi.nlm.nih.gov/books/NBK612584/
472 Casagrande SS, Park J, Herman WH, Bullard KM. Health insurance and diabetes. In: Lawrence JM, Casagrande SS, Herman WH, Wexler DJ, Cefalu WT, eds. Diabetes in America. eBook. National Institutes of Health; 2023. https://www.ncbi.nlm.nih.gov/books/NBK597725/
473 American Diabetes Association. Economic costs of diabetes in the U.S. in 2017. Diabetes Care. 2018;41(5):917-928. doi:10.2337/dci18-0007 29567642
474 Specht BJ, Wadwa RP, Snell-Bergeon JK, Nadeau KJ, Bishop FK, Maahs DM. Estimated insulin sensitivity and cardiovascular disease risk factors in adolescents with and without type 1 diabetes. J Pediatr. 2013;162(2):297-301. doi:10.1016/j.jpeds.2012.07.036 22921593
475 Haller MJ, Stein J, Shuster J, et al. Peripheral artery tonometry demonstrates altered endothelial function in children with type 1 diabetes. Pediatr Diabetes. 2007;8(4):193-198. doi:10.1111/j.1399-5448.2007.00246.x 17659060
476 Urbina EM, Wadwa RP, Davis C, et al. Prevalence of increased arterial stiffness in children with type 1 diabetes mellitus differs by measurement site and sex: the SEARCH for Diabetes in Youth Study. J Pediatr. 2010;156(5):731-737, 737 e1. doi:10.1016/j.jpeds.2009.11.011
477 Shah AS, Dolan LM, Gao Z, Kimball TR, Urbina EM. Racial differences in arterial stiffness among adolescents and young adults with type 2 diabetes. Pediatr Diabetes. 2012;13(2):170-5. doi:10.1111/j.1399-5448.2011.00798.x 21790919
478 Reynolds K, Saydah SH, Isom S, et al. Mortality in youth-onset type 1 and type 2 diabetes: the SEARCH for Diabetes in Youth study. J Diabetes Complications. 2018;32(6):545-549. doi:10.1016/j.jdiacomp.2018.03.015 29685480

FIGURE 1.

Algorithm for Classification of Pediatric Diabetes.

GADA, glutamic acid decarboxylase antibody; IA-2A, insulinoma-associated antibody 2; IAA, insulin autoantibody; MODY, maturity-onset diabetes of youth; ZnT8A, zinc transporter 8 antibody.

Flow chart showing that the classification of pediatric diabetes includes the presence of autoimmunity for type 1 and the absence of diabetes-related autoantibodies and evidence of insulin resistance or obesity for type 2.

FIGURE 2.

Prevalence of Type 1 Diabetes Among Youth Age 0–19 Years, by Age, Sex, and Race/Ethnicity.

In SEARCH, the surveillance denominator is the count of the age- and geography-eligible population based on Indian Health Service users (Arizona and New Mexico), health plan enrollees (California) and the U.S. Census (all other sites). MarketScan data are based on Medicaid claims with a denominator of subscribers or commercial claims with a denominator of pediatric healthcare utilizers. F, female; M, male; NH, Non-Hispanic; NHANES, National Health and Nutrition Examination Survey; NHIS, National Health Interview Survey; SEARCH, SEARCH for Diabetes in Youth study.

* Sex group-level estimates are not available.

† Sex and race/ethnicity-level estimates are not available.

SOURCE: References (59,60,61,62,63,64)

Bar graph showing the prevalence of type 1 and type 2 diabetes in youth increases with age and varies by sex, race/ethnicity and study population.

FIGURE 3.

Incidence of Type 1 and Type 2 Diabetes Among Youth Age 0–19 Years, by Age and Race/Ethnicity.

In SEARCH, the surveillance denominator is the count of the age- and geography-eligible population based on Indian Health Service users (Arizona and New Mexico), health plan enrollees (California) and the U.S. Census (all other sites). NH, Non-Hispanic; SEARCH, SEARCH for Diabetes in Youth study.

* Race/ethnicity-level estimates are not available.

SOURCE: References (54,61,74,94,95)

Bar graph showing the incidence of type 1 diabetes in youth is highest for those age 10 to 14 years and the incidence of type 2 is highest for American Indian youth and lowest for non-Hispanic white youth.

FIGURE 4.

Adjusted Annualized Percentage Change in Incidence of Type 1 and Type 2 Diabetes Among Youth, by Race/Ethnicity.

Adjusted annualized percentage change (AAPC) reported between 2002–2003 and 2017–2018 for SEARCH, 2002–2003 and 2012–2013 for British Columbia, Canada, and 2001 and 2015 for Clinformatics. In SEARCH, the surveillance denominator is the count of the age- and geography-eligible population based on Indian Health Service users (Arizona and New Mexico), health plan enrollees (California) and the U.S. Census (all other sites). Error bars represent standard errors. NH, non-Hispanic; NS, not significant; SEARCH, SEARCH for Diabetes in Youth study.

SOURCE: References (54,61,74,94)

Bar graph showing an upward trend in age, sex, and race ethnicity adjusted incidence of type 1 and type 2 diabetes in youth between 2002 and 2018.

FIGURE 5.

Prevalence of Type 2 Diabetes Among Youth Age 0–19 Years, by Age, Sex, and Race/Ethnicity.

In SEARCH, the surveillance denominator is the count of the age- and geography-eligible population based on Indian Health Service users (Arizona and New Mexico), health plan enrollees (California) and the U.S. Census (all other sites). MarketScan data are based on Medicaid claims with a denominator of subscribers or commercial claims with a denominator of pediatric healthcare utilizers. F, female; M, male; NH, Non-Hispanic; NHANES, National Health and Nutrition Examination Survey; SEARCH, SEARCH for Diabetes in Youth study.

* Sex group-level estimates are not available.

SOURCE: References (59,62,63)

FIGURE 6.

Three-Year Annual Average Death Rates From Diabetes Per 1 Million Youth Age ≤19 Years, by Race/Ethnicity, U.S., 2000–2014.

Based on diabetes as the underlying cause of death, using International Classification of Diseases, Tenth Revision (ICD-10) codes E10–E14.

SOURCE: Reference (463)

Line graph showing a decreasing trend in mortality from diabetes among all youth between 2000 and 2014 but stable death rates for Hispanic youth.

TABLE 1.

Occurrence of Diabetic Ketoacidosis and Hypoglycemia in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Diabetic Ketoacidosis
Type 1 Diabetes
Boston Children’s Hospital, MA, 1990–1999 (187) | n=223; onset age <6 yrs; hospitalized at onset | Glucose >300 mg/dL, venous pH <7.3, and/or serum HCO_3_ or total CO_2_ <15 mmol/L by chart review | Prevalence of DKA at diagnosis age <6 yrs: 43.7% | Single hospital case series, including cases transferred from other hospitals
New York Children’s Hospital, NY, 1995–1998 (188) | n=139; onset age <18 yrs | Hyperglycemia, with ketosis and pH <7.3 | Prevalence of DKA at diagnosis, by age (yrs): 0–18: 38.0% 0–5: 54.5% 6–10: 31.3% 11–18: 29.8% | Single hospital case series; not population-based; delay in diagnosis increased DKA prevalence 2.8-fold
Barbara Davis Center, CO, 1996–2000 (195) | n=1,243; onset age <19 yrs; median age 13.0 yrs; followed for 3.5 yrs | Episode of hyperglycemia and ketoacidosis from emergency department visit or hospitalization, excluding at diagnosis | Incidence of DKA per 100 person-yrs, by sex and age at last visit: All: 8.0 Age (yrs)……[underlined: Boys]…..[underlined: Girls] <7....................7.0..........4.0 7–12................4.9..........8.0 ≥13..................7.5.........12.0 | Clinic-based; includes ~80% of state cases; associations with A1C, insulin dose, insurance, psychiatric disorder in older children
SEARCH, 2001, 2002–2005 (40,189,190,191,192) | n=1,656; onset age <20 yrs | ≥1 criteria: a) HCO_3_ <15 mmol/L or pH <7.25 (venous) or <7.3 (arterial); b) ICD-9 code 250.1; or c) diagnosis of DKA in medical chart; all with hyperglycemia | Prevalence of DKA at diagnosis, by age (yrs) and race/ethnicity: All: 29.4% Non-Hispanic White 0–4: 28.9% 5–9: 18.5% 10–14: 24.0% 15–19: 15.8% Non-Hispanic Black 0–9: 30.8% 10–14: 25.9% 15–19: 16.7% Hispanic 0–9: 25.6% 10–14: 23.7% 15–19: 21.6% Asian 0–19: 27.9% Pacific Islander 0–19: 33.3% Asian-Pacific Islander 0–19: 26.1% | Population-based; no sex differences; associations with family income, health insurance, parental education
Barbara Davis Center, CO, 2002–2003 (186) | n=359 new-onset T1D youth; onset age <18 yrs | Any DKA: pH <7.3 HCO_3_ <15 mmol/L Severe DKA: pH <7.10 HCO_3_ <5 mmol/L | Prevalence of DKA at diagnosis: Any DKA: 28.4% By age (yrs) <4: 55.2% 4–8: 20.2% 9–12: 25.4% 13–18: 23.6% Uninsured/severe DKA: 50.0% Insured/severe DKA: 30.6% | Clinic-based; includes ~80% of state cases
SEARCH, 2002–2006, 2008 (212) | n=1,396; onset age <20 yrs | Blood HCO_3_ level <15 mmol/L, and/or a pH <7.25 (venous) or <7.30 (arterial or capillary), and/or a DKA diagnosis mentioned in the medical records | Prevalence of DKA at diagnosis: 28% | DKA at diagnosis associated with higher A1C over time
SEARCH, 2002–2010 (39) | n=5,615; onset age <20 yrs | ≥1 criteria: a) HCO_3_ <15 mmol/L or pH <7.25 (venous) or <7.3 (arterial); b) ICD-9 code 250.1; or c) diagnosis of DKA in medical chart; all with hyperglycemia | Prevalence of DKA at diagnosis: 2002–2003: 30.2% 2004–2005: 29.1% 2008–2010: 31.1% | Population-based; age and race/ethnicity differences; associations with income and private insurance; no trends over time
TEDDY, 2004–2010 (210) | n=119; onset ages <2 (n=40) and <5 yrs (n=79) | Multiple definitions; most common: pH <7.3 or HCO_3_ <15 mmol/L. If pH and HCO_3_ missing, then urine ketones >40 mEq/L, blood ketones >3 mmol/L, or physician diagnosis of DKA | Prevalence of DKA at diagnosis, by age (yrs): .................................[underlined: <2]...............[underlined: <5] SEARCH (U.S.)......50.0%.........36.4% Germany..................54.0%.........32.2% Sweden...................39.5%.........16.9% Finland....................44.8%.........18.7% TEDDY...................15.0%.........11.3% | TEDDY is a study of the etiology of early-onset T1D; close follow-up during study said to reduce DKA risk; not population-based.
TEDDY, 2004–2010 (211) | n=379; onset age <15 yrs | Multiple definitions; most common: pH <7.3 or HCO_3_ <15 mmol/L. If pH and HCO_3_ missing, then urine ketones >40 mEq/L, blood ketones >3 mmol/L, or physician diagnosis of DKA. | Prevalence of DKA at diagnosis: 6.1%
Pediatric Diabetes Consortium, 2009–2011 (207) | n=805; onset age <19 yrs | DKA defined by a pH <7.3 and/or HCO_3_ value <15 mEq/L | Total: 34.0% Across centers: 28%–40% | Not population-based; ≥1 antibodies required; associations with age, parental education; race/ethnicity differences
SEARCH, 2009–2012 and YDR (India), 2006–2012 (214) | n=4,078 SEARCH; n=2,108 YDR; onset age <20 yrs | Blood and medical records | Prevalence of DKA at diagnosis, by year and age at diagnosis: ........……......[underlined: SEARCH]…..[underlined: YDR] Year 2009...............28.9%..........27.3% 2010...............35.2%..........26.5% 2011...............36.9%..........26.1% 2012...............39.8%..........29.1% Age (yrs) 0–4.................43.7%..........36.7% 5–9.................35.2%..........30.0% 10–14.............35.4%..........30.5% 15–19.............26.6%..........18.1%
T1D Exchange Clinic Registry, 2010–2012 (194) | n=13,487; onset age <26 yrs; median diabetes duration 6.0 yrs | Self- or family report of hospitalization for DKA in prior year | Prevalence of ≥1 DKA episode in past year, by age (yrs): <6: 9.4% 6–12: 7.6% 13–17: 11.4% 18–25: 10.5% | Voluntary U.S. clinic-based registry; associations with A1C, income, and insurance; sex and race/ethnicity differences
SEARCH, 2010–2016 (208) | n=7,612; onset age <20 yrs | ≥1 criteria: a) HCO_3_ <15 mmol/L or pH <7.25 (venous) or <7.3 (arterial); b) ICD-9 code 250.1; or c) diagnosis of DKA in medical chart; all with hyperglycemia | Prevalence of DKA at diagnosis: 2010: 35.3% 2016: 40.6% | Population-based; age and race/ethnicity differences; associations with income and private insurance; increasing prevalence over time
National and International Registries, 2013–2022 (204) | n=109,494; age ≤18 yrs | | Aggregate event rate per 100 person-yrs: 2013: 3.1 2022: 2.2
Type 2 Diabetes
Toronto Hospital for Sick Children, Canada, 1994–2002 (213) | n=44; onset age <18 yrs | DKA not defined T2D: typical course and ≥2 risk factors (obesity, insulin resistance-related signs) | Prevalence of DKA at diagnosis: 8.0% | Hospital-based; higher in non-Hispanic Black and Southeast Asian youth; no DKA in non-Hispanic White or First Nation youth
SEARCH, 2001, 2002–2005 (40,189,190,191,192) | n=507; onset age <20 yrs | ≥1 of criteria: a) HCO_3_ <15 mmol/L or pH <7.25 (venous) or <7.3 (arterial); b) ICD-9 code 250.1; or c) diagnosis of DKA in medical chart; all with hyperglycemia | Prevalence of DKA at diagnosis, by race/ethnicity and age (yrs): All: 9.7% Non-Hispanic White 10–14: 8.8% 15–19: 2.6% Non-Hispanic Black 10–14: 10.9% 15–19: 13.1% Hispanic 10–14: 9.4% 15–19: 6.4% Asian 10–19: 6.3% | Population-based; no sex differences
SEARCH, 2002–2010 (39) | n=1,425; onset age <20 yrs | ≥1 criteria: a) HCO_3_ <15 mmol/L or pH <7.25 (venous) or <7.3 (arterial); b) ICD-9 code 250.1; or c) diagnosis of DKA in medical chart; all with hyperglycemia | Prevalence of DKA at diagnosis: 2002–2003: 11.7% 2004–2005: 6.3% 2008–2010: 5.7% | Population-based
SEARCH, 2009–2012, and YDR (India), 2006–2012 (214) | n=1,288 SEARCH; n=227 YDR; onset age 10–19 yrs | Blood and medical records | Prevalence of DKA at diagnosis, by age (yrs) at diagnosis: ..................[underlined: SEARCH].......[underlined: YDR] 10–14............6.9%...........8.4% 15–19............4.6%...........6.3%
Severe Hypoglycemia
Type 1 Diabetes
T1D Exchange Clinic Registry, 2010–2012 (194) | n=13,487; onset age <26 yrs; median diabetes duration 6.0 yrs | Self- or family report of seizure or loss of consciousness | Prevalence (past year), by current age (yrs): <6: 9.6% 6–12: 5.2% 13–17: 6.3% 18–25: 6.9% | Clinic-based registry; more common among families with lower income, and no private insurance; associations with diabetes duration, and A1C; race/ethnicity differences
SEARCH, 2011–2015 (227) | n=2,399; onset age <20 yrs; mean diabetes duration 8.0 yrs | Self- or family report of needing assistance, glucagon use, emergency department, or hospitalization | Prevalence (past 6 months): 7.0% | Population-based; associations with age, BMI, activity, A1C; no race/ethnicity differences
National and International Registries, 2013–2022 (204) | n=109,494; age ≤18 yrs | 2018 ISPAD Guidelines: severe cognitive impairment (including seizure/coma) requiring assistance | Aggregate event rate per 100 person-yrs: 2013: 3.0 2022: 1.7
Type 2 Diabetes
SEARCH, 2011–2015 (227) | n=341; onset age <20 yrs; mean diabetes duration 8.1 yrs | Self- or family report of needing assistance, glucagon use, emergency department, or hospitalization | Prevalence (past 6 months): 2.6% | Population-based; higher prevalence in T1D compared to T2D (7.0% vs. 2.6%), absolute difference 4.4%

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A conversion formula for glucose values is available in the Conversions section. A1C, glycated hemoglobin; BMI, body mass index; CO_2_, carbon dioxide; DKA, diabetic ketoacidosis; HCO_3_, bicarbonate; ICD-9, International Classification of Diseases, Ninth Revision; ISPAD, International Society for Pediatric and Adolescent Diabetes; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TEDDY, The Environmental Determinants of Diabetes in the Young; YDR, Registry of Youth Onset Diabetes in India.

SOURCE: References are listed within the table.

TABLE 2.

Retinopathy in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Type 1 Diabetes
SEARCH, 2002–2019 (252) | n=976 with both visits; onset age <20 yrs; mean diabetes duration 7.7 and 12.5 yrs | 45° non-mydriatic camera photos with central reading; two images obtained over an average of 4.6 yrs apart | Prevalence of any retinopathy: 1st visit: 21.0% 2nd visit: 52.0% Progressed to more severe grades: 38.8% Regressed to less severe grades: 4.3% Evidence of proliferative retinopathy: 0.8% | Population-based; race/ethnicity differences
SEARCH, 2011–2015 (184) | n=1,710; onset age <20 yrs; mean diabetes duration 7.9 yrs | 45° non-mydriatic camera photos with central reading | Prevalence of moderate-severe retinopathy: 5.6% | Population-based; race/ethnicity differences
Type 2 Diabetes
Pima Indians, AZ, 1965–2002 (259) | n=178; onset age <20 yrs | Dilated direct ophthalmoscopy | Incidence of any retinopathy, by diabetes duration and age: ..........................Duration (yrs)......... Age (yrs).....[underlined: 5–10]....[underlined: 10–15]....[underlined: 15–20] <20………...9.7…..42.3……68.7 40–59……...35.1….85.6……99.1 | Population-based; dynamic cohort
Manitoba, Canada, Hospital 1986–2007 (258) | n=342; mean age at baseline 13.5 yrs | Insurance plan records, ICD codes, prescriptions, clinical laboratory data from center | Prevalence at end of follow-up: 11.7% | Not population-based; clinic cares for 86% of all youth with diabetes in the province; no difference in prevalence for T2D vs. T1D (11.7% vs. 13.8%).
SEARCH, 2002–2019 (252) | n=229 with both visits; onset age <20 yrs; mean diabetes duration 7.5 and 12.4 yrs | 45° non-mydriatic camera photos with central reading; two images obtained over a mean of 4.4 yrs | Prevalence of any retinopathy: 1st visit: 31.0% 2nd visit: 55.7% Progressed to more severe grades: 41.3% Regressed to less severe grades: 5.0% Proliferative retinopathy: 3.1% | Population-based; race/ethnicity differences; associations with A1C, blood pressure, BMI
TODAY, 2010–2011 (255) | n=517; onset age 10–17 yrs; mean diabetes duration 4.9 yrs | Dilated seven standard field retinal photos with central reading | Prevalence of any retinopathy: 13.7% | RCT; associations with age, diabetes duration, A1C
TODAY2, 2010–2011, 2017–2018 7 yrs apart (256) | n=367; onset age 10–17 yrs | Dilated seven standard field retinal photos with central reading | Prevalence of any retinopathy: 49.0% 3+ step progression: 25.3% Very mild to mild nonproliferative: 39.0% Moderate to severe nonproliferative: 6.0% Proliferative retinopathy: 3.8% | RCT and observational follow-up; associations with A1C, blood pressure, BMI, triglycerides, C-peptide, hypertension, kidney disease; no sex or race/ethnicity differences
SEARCH, 2011–2015 (184) | n=267; onset age <20 yrs; mean diabetes duration 7.9 yrs | 45° non-mydriatic camera photos with central reading | Prevalence of moderate-severe retinopathy: 9.1% | Population-based; higher prevalence in T2D compared to T1D (9.1% vs. 5.6%), absolute difference 3.5%

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A1C, glycated hemoglobin; BMI, body mass index; ICD, International Classification of Diseases; RCT, randomized controlled trial; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TODAY, Treatment Options for Type 2 Diabetes in Adolescents and Youth; TODAY2, long-term observational follow-up of the TODAY trial.

SOURCE: References are listed within the table.

TABLE 3.

Kidney Disease in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Type 1 Diabetes
Manitoba, Canada, Hospital, 1986–2007 (268) | n=1,011; mean age at baseline 8.9 yrs | Insurance plan records, ICD codes, prescriptions, clinical laboratory data from center | Prevalence at end of follow-up: Persistent moderate albuminuria: 12.7% Persistent severe albuminuria: 1.6% Renal complications: 2.7% Renal failure: 1.4% ESRD: 0% | Not population-based; clinic cares for 86% for all youth with diabetes in the province.
SEARCH, 2001–2003 (266) | n=2,885; onset age <20 yrs; mean diabetes duration 3.7 yrs | ACR ≥30 μg/mg | Prevalence of elevated ACR: 9.2% | Population-based; no race/ethnicity differences
T1D Exchange, 2010–2012 (267) | n=7,549; onset age <20 yrs; mean diabetes duration 6.5 yrs | Clinical diagnosis of persistent moderate albuminuria and last ACR ≥30 mg/g or treatment with ACEi or ARB | Prevalence of persistent moderate albuminuria: 4.4% | Not population-based; associations with age, diabetes duration, A1C, blood pressure, BMI; 64% with diagnosis were not treated with an ACEi or ARB; sex differences.
SEARCH, 2011–2015 (184) | n=1,541; onset age <20 yrs; mean diabetes duration 7.9 yrs | ACR ≥30 μg/mg, or eGFR ≤60 mL/min/1.73 m^2^ | Prevalence of kidney disease: 5.8% | Population-based; race/ethnicity differences
Type 2 Diabetes
Pima Indians, AZ, 1965–2002 (259) | n=178; onset age <20 yrs | Spot urine protein:creatinine ratio ≥0.5 (g protein/g creatinine) | Incidence of any kidney disease, by diabetes duration and age: ...........................Duration (yrs)....... Age (yrs).....[underlined: 5–10]....[underlined: 10–15]....[underlined: 15–20] <20………..13.9…..51.8…...90.1 40–59….......18.8…..43.2…..94.3 | Population-based; dynamic cohort
Pima Indians, AZ, 1965–2002 (285) | n=96; onset age <20 yrs | Dialysis, transplant, or death from diabetic nephropathy | Incidence of ESRD per 1,000 person-yrs: Youth-onset: 25.0 Adult-onset: 5.4 | Population-based; dynamic cohort; higher prevalence in youth vs. adult T2D (fivefold)
Manitoba, Canada, Hospital, 1986–2007 (268) | n=342; mean age at baseline 13.5 yrs | Insurance plan records, ICD codes, prescriptions, clinical laboratory data from center | Prevalence at end of follow-up: Persistent moderate albuminuria: 26.9% Persistent severe albuminuria: 4.7% Renal complications: 8.9% Renal failure: 6.7% ESRD: 2.3% | Not population-based; clinic cares for 86% for all youth with diabetes in the province; higher prevalence in T2D vs. T1D; fourfold increased risk renal failure.
SEARCH, 2001–2003 (266) | n=374; onset age <20 yrs; mean diabetes duration 1.9 yrs | ACR ≥30 μg/mg | Prevalence of elevated ACR: 22.2% | Population-based; higher prevalence in T2D vs. T1D
TODAY, 2004–2011 (281) | n=699; onset age 10–17 yrs | Moderate albuminuria: two of three ACR ≥30 µg/mg in 3 months | Prevalence of microalbuminuria: 18.0% | RCT; mean follow-up 3.9 yrs
SEARCH, 2011–2015 (184) | n=221; onset age <20 yrs; mean diabetes duration 7.9 yrs | ACR ≥30 μg/mg or eGFR ≤60 mL/min/1.73 m^2^ | Prevalence of kidney disease: 19.9% | Population-based; higher prevalence in T2D compared to T1D (19.9% vs. 5.8%), absolute difference 14.0%
TODAY2, 2011–2020 (185) | n=500; onset age 10–17 yrs; diabetes duration <2 yrs | Moderate albuminuria: two of three ACR ≥30 µg/mg in 3 months | Baseline: 8.0% 15-yr cumulative incidence: 54.8% | RCT and observational follow-up; mean follow-up 10.2 yrs

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A1C, glycated hemoglobin; ACEi, angiotensin-converting enzyme inhibitor; ACR, albumin:creatinine ratio; ARB, angiotensin II receptor blocker; BMI, body mass index; eGFR, estimated glomerular filtration rate; ESRD, end-stage renal disease; ICD, International Classification of Diseases; RCT, randomized controlled trial; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TODAY, Treatment Options for Type 2 Diabetes in Adolescents and Youth; TODAY2, long-term observational follow-up of the TODAY trial.

SOURCE: References are listed within the table.

TABLE 4.

Neuropathy in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Diabetic Peripheral Neuropathy
Type 1 Diabetes
SEARCH, 2011–2015 (305) | n=1,734; onset age <20 yrs; mean diabetes duration 7.2 yrs | MNSI Exam >2 | Prevalence of DPN: 7% | Population-based; associations with age, smoking, diabetes duration, blood pressure, obesity, cholesterol, and A1C
Type 2 Diabetes
SEARCH, 2011–2015 (305) | n=258; onset age <20 yrs; mean diabetes duration 7.9 yrs | MNSI Exam >2 | Prevalence of DPN: 22% | Population-based; associations with age, smoking, diabetes duration, cholesterol, but not A1C; sex differences
TODAY2, 2011–2020 (310) | n=674; onset age 10–17 yrs; diabetes duration <2 yrs | MNSI Exam >2, Survey ≥4, <8/10 Monofilament each at ≥2 consecutive visits | Prevalence: .............................[underlined: Baseline]......[underlined: Follow-up] Exam >2..................3.1%............25.4% Survey ≥4................7.3%............17.7% Exam +/- Survey......9.8%............34.9% Monofilament...........0.3%............10.0% | RCT and observational follow-up; mean follow-up 10.2 yrs; associations with age, BMI, A1C, and blood pressure; sex differences
Cardiovascular Autonomic Neuropathy
Type 1 Diabetes
SEARCH CVD Substudy, 2009–2011, 2 of 5 sites (320) | n=354; onset age <20 yrs; mean diabetes duration 9.8 yrs n=176 controls | SDNN, RMSSD, LF, HF, LF:HF | Prevalence of CAN: 22% Compared to controls, youth with T1D had lower SDNN, RMSSD, PNN50, and lower LF power. | Population-based; associations with age, cholesterol, triglycerides, and microalbuminuria; sex differences
SEARCH, 2011–2015 (321) | n=1,646; onset age <20 yrs; mean diabetes duration 8 yrs | ≥3 of 5 HRV abnormalities based on 5th/95th percentile of age- and sex-matched controls | Prevalence of CAN: 12% | Population-based
SEARCH, 2011–2015 (323) | n=1,327; onset age <20 yrs; mean diabetes duration 7.9 yrs | ≥3 of 5 HRV abnormalities based on 5th/95th percentile of age- and sex-matched controls | Prevalence of CAN: 8.6% CAN and arterial stiffness co-occurred more frequently than expected. | Population-based
SEARCH, 2011–2015 and 2015–2019, 4.6 yrs apart (322) | n=864; onset age <20 yrs | SDNN, RMSSD, PNN50, LF, HF, LF:HF | Significant worsening of SDNN, PNN50, RMSSD over 4.6 yrs; median change ranged from 14.5% to 20.8%. | Population-based; associations with A1C, blood pressure, waist circumference, and triglycerides
Type 2 Diabetes
SEARCH, 2011–2015 (321) | n=252; onset age <20 yrs; mean diabetes duration 8 yrs | ≥3 of 5 HRV abnormalities based on 5th/95th percentile of age- and sex-matched controls | Prevalence of CAN: 17% | Population-based; associations with triglycerides, and UAER; race/ethnicity differences
SEARCH, 2011–2015 (328) | n=185; onset age <20 yrs; mean diabetes duration 7.8 yrs | SDNN, RMSSD, LF, HF, LF:HF | Participants with vs. without T2D + arterial stiffness had lower SDNN, RMSSD, PNN50. | Population-based
SEARCH, 2011–2015 and 2015–2019, 4.6 yrs apart (322) | n=192; onset age <20 yrs | SDNN, RMSSD, PNN50, LF, HF, LF:HF | Significant worsening of SDNN, PNN50, RMSSD over 4.6 yrs; median change ranged from 23.1% to 66.9%; significantly lower SDNN, PNN50, RMSSD in T2D vs. T1D at both time points; no difference in change over time. | Population-based; associations with A1C, diabetes duration, triglycerides, blood pressure, physical activity; sex differences
TODAY2, 2013–2014 (326) | n=397; onset age 10–17 yrs n=133 controls | SDNN, RMSSD, PNN50, LF, HF, LF:HF; CAN defined as ≥3 of 6 abnormalities based on the 5th/95th percentile of controls with obesity | Prevalence of CAN: 8.1% Compared to controls, youth with T2D had lower SDNN, RMSSD, PNN50, and higher LF:HF. | RCT and observational follow-up; associations with A1C, diabetes duration, albuminuria, hypertension, and higher PWV carotid femoral; sex and race/ethnicity differences
TODAY2, 2013–2014, 2018–2019, 5 yrs apart (327) | n=304; onset age 10–17 yrs | SDNN, RMSSD, PNN50, HF, LF:HF | Significant worsening of all indices over 5 yrs; median change ranged from 10.1% to 50.0%; SDNN <70 ms (associated with fourfold higher risk of death in adults) rose from 73.0% to 83.5%. | RCT and observational follow-up; associations with A1C, and with worsening HRV over time

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A1C, glycated hemoglobin; BMI, body mass index; CAN, cardiovascular autonomic neuropathy; CVD, cardiovascular disease; DPN, diabetic peripheral neuropathy; HF, high frequency; HRV, heart rate variability; LF, low frequency; MNSI, Michigan Neuropathy Screening Instrument; PNN50, percentage of absolute differences in successive NN (normal-to-normal) values >50 ms; PWV, pulse wave velocity; RCT, randomized controlled trial; RMSSD, root mean square of successive differences between normal heartbeats; SDNN, standard deviation of normal-to-normal; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TODAY2, long-term observational follow-up of the TODAY (Treatment Options for Type 2 Diabetes in Adolescents and Youth) trial; UAER, urinary albumin excretion rate.

SOURCE: References are listed within the table.

TABLE 5.

Metabolic Dysfunction-Associated Steatotic Liver Disease in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Type 1 Diabetes
Arkansas Children’s Hospital, AR, 2019–2022 (335) | n=49; mean age 14 yrs; diabetes duration 5 yrs n=28 controls | FibroScan®; MASLD defined by CAP score ≥241 dB/m | Prevalence of MASLD: T1D + obesity: 66% T1D + no obesity: 17% Controls + obesity: 71% | Clinic-based; associations with weight, BMI, HDL, and A1C
University of Colorado, Colorado Children’s Hospital, Aurora, CO, 2005–2010 (336) | n=12; mean age 15.2 yrs n=12 controls | IMCL by MRI | No difference in IMCL between T1D and controls, suggesting lack of ectopic fat accumulation in T1D
University of Colorado, Colorado Children’s Hospital, Aurora, CO, 2005–2010 (337) | n=35; median age 16 yrs; median BMI 24 kg/m^2^ n=22 controls | Liver transaminases, liver fat by MRI | No differences in liver fat or ALT/AST levels between T1D and controls, despite T1D having liver insulin resistance assessed with hyperinsulinemic-euglycemic insulin clamp paired with glucose tracers
Type 2 Diabetes
Barbara Davis Center, CO, 1996–2002 (338) | n=115, mean age 15.4 yrs | Chart review of liver-related blood tests | Prevalence of elevated ALT: 48% Above normal limit: 1–2x: 39% 2–3x: 26% >3x: 35% | Clinic-based; no associations with age, BMI, A1C, lipids; prevalence of ALT higher in males than females
Manitoba, Canada, Hospital, NA (346) | n=27; mean age 15 yrs n=110 controls | Spectroscopy | Prevalence: Hepatic steatosis in T2D: 64% Hepatic steatosis in controls: 27% Elevated ALT in T2D: 31% | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
Manitoba, Canada, Hospital, 1997–2002 (347) | n=227; mean age 15.3 yrs | Liver transaminases | Prevalence of elevated ALT: 22% | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
TODAY, 2004–2011 (342) | n=679; onset 10–17 yrs; diabetes duration <2 yrs | Liver transaminases | .........................[underlined: Baseline].....[underlined: 6 Months].....[underlined: 24 Months] ALT (U L-1) No MetS.............25.49...........21.80............20.87 MetS...................32.99...........33.79............37.23 AST (U L-1) No MetS.............22.80...........22.88............23.55 MetS...................24.60...........27.78............28.89 | RCT; mean follow-up 3.9 yrs; exclusion criteria included ALT/AST levels >2.5 times the upper limit of normal
Phoenix Children’s Hospital, AZ, 2005–2006 (339) | n=57; mean age 13.5 yrs | Chart review of liver-related blood tests | Prevalence, by race/ethnicity: ................................................[underlined: Any].....[underlined: 2x above normal] Elevated ALT Non-Hispanic White................88%..............22% Non-Hispanic Black................20%...............0% Hispanic..................................71%..............39% Elevated AST Non-Hispanic White................11%...............0% Non-Hispanic Black..................0%................0% Hispanic..................................53%..............21% | Clinic-based
University of Colorado, Colorado Children’s Hospital, Aurora, CO, 2009–2015 (343) | n=27; median age 15.6 yrs; BMI 96.1 percentile n=21 controls | Liver fat and visceral fat by MRI; MASLD defined by hepatic fat ≥5.5% | Prevalence of MASLD: T2D: 33% Controls: 24%
Pediatric Diabetes Consortium Registry, 2012–2018 (340) | n=1,217; mean age of onset 13.4 yrs | Medical diagnosis by clinical practitioner, self-reported | Prevalence of MASLD, by race/ethnicity: Non-Hispanic White: 11% Non-Hispanic Black: 2% Hispanic: 9%
Cincinnati Children’s Hospital, Cincinnati, OH; University of Colorado, Colorado Children’s Hospital, Aurora, CO; ST2OMP Study, 2020–2025 (345) | n=56; mean age 16 yrs; BMI 43.8 kg/m^2^; diabetes duration 1.7 yrs | Liver transaminases, PDFF by MRI, liver stiffness by MR elastography; MASLD defined by PDFF ≥5% | Elevated ALT: 76.4% PDFF: 89.0% Stiffness: 14.8% | RCT; PDFF and ALT higher in male vs. females and youth not taking GLP-1 receptor agonist; non-Hispanic White youth had highest stiffness.

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A1C, glycated hemoglobin; ALT, alanine aminotransferase; AST, aspartate aminotransferase; BMI, body mass index; CAP, controlled attenuation parameter; GLP-1, glucagon-like peptide-1; HDL, high-density lipoprotein; IMCL, intramyocellular lipid; MASLD, metabolic dysfunction-associated steatotic liver disease; MetS, metabolic syndrome; MR/MRI, magnetic resonance/imaging; NA, not available; PDFF, proton density fat fraction; RCT, randomized controlled trial; ST2OMP study, Surgical or Medical Treatment for Pediatric Type 2 Diabetes trial; T1D, type 1 diabetes; T2D, type 2 diabetes; TODAY, Treatment Options for Type 2 Diabetes in Adolescents and Youth.

SOURCE: References are listed within the table.

TABLE 6.

Cardiovascular Risk Factors in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Glycemic Control
Type 1 Diabetes
Joslin Diabetes Center, MA, 1997–1998, 2002–2003 (two cohorts) (374) | 1997–1998, n=299 2002–2003, n=152 age 8–16 yrs; mean diabetes duration 5–6 yrs | | Mean A1C, by period of enrollment: .......................[underlined: 1997–1998].........[underlined: 2002–2003] Baseline...............8.7%...................8.4% Follow-up............9.0%...................8.7% | Clinic-based sequential recruitment; 2 yrs of follow-up
SEARCH, 2001–2005 (372) | n=3,947; onset age <20 yrs | Age-specific ADA criteria Good control: A1C <7.5% Poor control: A1C ≥9.5% | Prevalence of poor control: All: 17% By age (yrs) 0–5: 8.0% 6–12: 11.3% 13–18: 23.3% 19–22: 28.5% Diabetes duration (mos) <12: 7.5% 12–23: 15.1% 24–47: 18.1% ≥48: 25.3% Race/ethnicity Non-Hispanic White: 12.3% Non-Hispanic Black: 35.5% Hispanic: 27.3% Asian or Pacific Islander: 26.0% American Indian: 52.2% | Population-based registry; 47% response to exam
SEARCH, 2002–2019 (three cohorts) (377) | 2002–2007, n=3,398 2008–2013, n=2,184 2014–2019, n=1,742 | | Mean A1C, by study period and diabetes duration (yrs): ...............[underlined: 2002–2007].....[underlined: 2008–2013].....[underlined: 2014–2019] Overall.........8.5%...............8.9%..............8.8% 1–4...............8.5%...............8.6%..............8.7% 5–9...............8.6%...............9.1%..............9.2% ≥10...............8.6%...............9.3%..............9.0% | Population-based; significant increase over time (p<0.0001)
National and International Registries, 2013–2022 (204) | n=109,494; age ≤18 yrs | | Aggregate mean A1C: 2013: 8.2% (66.5 mmol/mol) 2022: 7.6% (59.4 mmol/mol) | Proportion who achieved A1C targets of <7% (<53 mmol/mol) increased from 19.0% to 38.8% (p<0.0001).
Type 2 Diabetes
SEARCH, 2001–2005 (372) | n=552; onset age <20 yrs | Age-specific ADA criteria Good control: A1C <7.5% Poor control: A1C ≥9.5% | Prevalence of poor control: All: 27% By age (yrs) 6–12: 15.6% 13–18: 23.0% ≥19: 47.2% Diabetes duration (mos) <12: 12.6% 12–23: 23.2% 24–47: 36.3% ≥48: 48.9% Race/ethnicity Non-Hispanic White: 12.2% Non-Hispanic Black: 22.3% Hispanic: 27.4% Asian or Pacific Islander: 36.4% American Indian: 43.8% | Population-based registry; 47% response to exam
SEARCH, 2002–2019 (three cohorts) (377) | 2002–2007, n=379 2008–2013, n=327 2014–2019, n=519 | | Mean A1C, by study period and diabetes duration (yrs): ...............[underlined: 2002–2007].....[underlined: 2008–2013].....[underlined: 2014–2019] Overall..........8.7%..............8.3%...............8.6% 1–4...............8.4%...............7.9%...............8.2% 5–9...............9.6%...............8.8%...............9.2% ≥10................NA.................8.4%..............10.1% | Population-based
TODAY2, 2011–2020 (185) | n=500; onset age 10–17 yrs; diabetes duration <2 yrs | | Prevalence of good and poor control: A1C.........[underlined: Baseline].....[underlined: 15 yrs] <6%..........75.0%.......19.0% ≥10%..........0%..........34.0% | RCT and observational follow-up; mean follow-up during trial was 3.9 yrs
Elevated Blood Pressure
Type 1 Diabetes
SEARCH, 2002–2005 (389) | n=3,691; onset age <20 yrs | ≥95th percentile for age, sex, and height, regardless of medication Healthy weight: <85th percentile Overweight: 85th–94.9th percentile Obesity: ≥95th percentile of U.S. youth | Prevalence of hypertension: All: 5.9% BMI category Healthy weight: 4.8% Overweight: 6.3% Obesity: 11.1% A1C <7.5%: 4.3% 7.5%–9.5%: 5.2% ≥9.5%: 8.4% | Population-based; 47% of eligible had examination; only 7.4% of those with hypertension were aware of their condition, and only 1.5% were treated.
SEARCH, 2011–2015 (184) | n=1,743; onset age <20 yrs; mean diabetes duration 7.9 yrs | ≥95th percentile for age, or relevant therapy | Prevalence of hypertension: 10.1% | Population-based; race/ethnicity differences
SEARCH, 2011–2015 (391) | n=1,518; onset age <20 yrs; mean diabetes duration 9.1 yrs | Prehypertension 90th–95th percentile for age, sex, height (youth <13 yrs), 120–129/<80 mmHg (youth ≥13 yrs and adults) Hypertension ≥95th percentile for age, sex, height (youth <13 yrs), 130/80 or higher mmHg (youth ≥13 yrs and adults), or relevant therapy | Prevalence: Baseline (prehypertension): 8.0% Follow-up (hypertension): 14.8%
Type 2 Diabetes
Manitoba, Canada, Hospital, 1997–2002 (390) | n=99; mean age 15.3 yrs | Chart review of clinical parameters; abnormal is >95th percentile of NHANES reference population | Prevalence of hypertension (age 7–17 yrs): SBP: 13% DBP: 6% | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
SEARCH, 2002–2005 (389) | n=410; onset age <20 yrs | ≥95th percentile for age, sex, and height, regardless of medication Healthy weight: <85th percentile Overweight: 85th–94.9th percentile Obesity: ≥95th percentile of U.S. youth | Prevalence of hypertension: All: 23.7% BMI category Healthy weight: 0% Overweight: 17.1% Obesity: 26.5% A1C <7.5%: 19.7% 7.5–9.5%: 28.6% ≥9.5%: 23.5% | Population-based; 47% of eligible had examination; only 31.9% of those with hypertension were aware of their condition, and 11.8% were treated.
TODAY, 2004–2011 (290) | n=699; onset age 10–17 yrs; diabetes duration <2 yrs | ≥95th percentile for age, sex, and height, 130/80 mmHg or higher on two consecutive occasions | Prevalence of hypertension: Baseline: 11.6% Follow-up: 33.8% | RCT; mean follow-up 3.9 yrs; associations with BMI; sex differences
SEARCH, 2011–2015 (184) | n=272; onset age <20 yrs; mean diabetes duration 7.9 yrs | ≥95th percentile for age, or relevant therapy | Prevalence of hypertension: 21.6% | Population-based; higher prevalence in T2D compared to T1D (21.6% vs. 10.1%), absolute difference 11.5%
SEARCH, 2011–2015 (391) | n=177; onset age <20 yrs; mean diabetes duration 10.7 yrs | Prehypertension 90th–95th percentile for age, sex, height (youth <13 yrs), 120–129/<80 mmHg (youth ≥13 yrs and adults) Hypertension ≥95th percentile for age, sex, height (youth <13 yrs), 130/80 or higher mmHg (youth ≥13 yrs and adults), or relevant therapy | Prevalence: Baseline (prehypertension): 23.2% Follow-up (hypertension): 35.6% | Population-based; T2D more likely to develop hypertension compared to T1D (35.6% vs. 14.8%), p<0.0001
TODAY2, 2011–2020 (355) | n=677; onset age 10–17 yrs; diabetes duration <2 yrs | ≥95th percentile for age, sex, and height, 130/80 mmHg or higher on three consecutive occasions, or a single elevated value followed by initiation of therapy | Baseline: 19.2% 14-yr cumulative incidence: 59.2% 27.8% reported antihypertensive medication use | RCT and observational follow-up; mean follow-up 10.2 yrs; associations with A1C, BMI, and insulin sensitivity; sex and race/ethnicity differences
Dyslipidemia
Type 1 Diabetes
Colorado Specialty Clinic, CO, 1994–2004 (402) | n=360; mean age 13.6 yrs; diabetes duration 4.5 yrs | TC ≥200 mg/dL Non-HDL ≥130 mg/dL HDL <35 mg/dL | Prevalence of sustained dyslipidemia: TC: 16.9% Non-HDL: 27.8% HDL: 3.3% | Clinic-based; mean follow-up 2.9 yrs; associations with A1C and BMI
Colorado Specialty Clinic, CO, 2000–2004 (396) | n=682; mean age 12.6 yrs; diabetes duration 3.9 yrs NHANES 2001–2002 | TC >200 mg/dL Non-HDL ≥130 mg/dL HDL <35 mg/dL | Prevalence of abnormal lipids: .............................[underlined: Diabetes].....[underlined: NHANES] TC...........................15.4%.........11.2% HDL..........................3.5%...........5.7% Either abnormal.......18.6%.........16.3% | Clinic-based; associations with A1C
SEARCH, 2001–2002 (397) | n=2,165; onset age <20 yrs | TC >200 mg/dL LDL >130 mg/dL HDL <40 mg/dL TG >200 mg/dL | Prevalence of abnormal lipids by age (yrs): ...............[underlined: <10].....[underlined: 10–19] TC..........12%......19% LDL........11%......15% HDL.........7%......12% TG............0%.......5% | Population-based
SEARCH, 2002–2005 (400) | n=1,193; onset age <20 yrs | Association of change in glycemic control to change in level of lipids over time; example is at A1C 8.0% at 6 months follow-up. | ............................[underlined: Change in A1C].....[underlined: Change in TC] Progressed.....................+1%...................+6.9 Regressed......................+2%..................+12.3 Stable normal..................-1%....................-3.9 Stable abnormal..............-2%....................-9.3 | Population-based; mean follow-up 2 yrs; all lipids significantly associated with changes in A1C over time.
SEARCH Case-Control, 2003–2006 (399) | n=512; mean age 13.9 yrs; diabetes duration 2.2 yrs n=188 controls; mean age 14.4 yrs | TC ≥200 mg/dL LDL ≥130 mg/dL TG ≥150 mg/dL HDL ≤35 mg/dL ApoB ≥90 mg/dL LDL Rf ≤0.237 Suboptimal A1C: ≥7.5% Optimal A1C: <7.5% | Prevalence of abnormal lipids, by A1C: ...............[underlined: Suboptimal].....[underlined: Optimal].....[underlined: Controls] TC...............15.6%...........7.4%..........8.6% HDL..............5.0%...........7.6%.........10.3% LDL.............12.1%............7.3%..........8.2% TG................8.7%............1.3%..........8.4% ApoB...........20.4%...........10.3%.........4.6% LDL Rf.........22.7%..........24.9%........10.6% | Population-based; 64% of eligible participated
SEARCH, 2011–2015 (401) | n=1,478; onset age <20 yrs; mean diabetes duration 8.1 yrs | Non-HDL >130 mg/dL HDL <35 mg/dL | Prevalence: ..............................[underlined: Non-HDL].....[underlined: HDL] Progressed................19%............3% Regressed..................5%.............3% Stable normal............69%...........94% Stable abnormal.........7%.............1% | Population-based; excluded participants on lipid-lowering medications; mean follow-up 7.1 yrs; associations with A1C and waist-to-hip-ratio; sex differences
Type 2 Diabetes
Manitoba, Canada, Hospital, 1997–2002 (390) | n=99; mean age 15.3 yrs n=249 First Nation youth controls | Chart review of clinical lipid parameters; abnormal is >75th or <25th percentile of NHANES reference population | Prevalence of abnormal lipids (age 7–17 yrs): ..............[underlined: Cases]......[underlined: Controls] TC..........75.8%.......60.0% HDL.......51.5%.......35.4% LDL........73.7%......41.4% TG..........65.7%.......43.0% ApoB......72.3%.......43.3% | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region
SEARCH, 2001–2002 (397) | n=283; onset age <20 yrs | TC >200 mg/dL Non-HDL ≥130 mg/dL HDL <40 mg/dL LDL >130 mg/dL TG >200 mg/dL | Prevalence of abnormal lipids (age 10–19 yrs): TC: 33% Non-HDL: 55% HDL: 44% LDL: 24% TG: 26% | Population-based; mean concentrations were significantly higher in T2D vs. T1D for all.
TODAY, 2004–2011 (405) | n=699; onset age 10–17 yrs | LDL >100 md/dL TG ≥150 mg/dL | Prevalence: LDL Baseline: 28.1% Follow-up: 34.7% TG Baseline: 21.0% Follow-up: 23.3% | RCT; mean follow-up 3.9 yrs
SEARCH, 2011–2015 (404) | n=212; onset age <20 yrs; mean diabetes duration 7.9 yrs | HDL <35 mg/dL LDL >100 mg/dL TG >150 mg/dL | Prevalence: ...............................[underlined: HDL].......[underlined: LDL]........[underlined: TG] Progressed............12.3%.....15.6%.....17.5% Regressed.............11.3%.....12.7%.....10.8% Stable normal........62.3%....42.9%.....55.7% Stable abnormal....14.2%....28.8%.....16.0% | Population-based; excluded participants on lipid-lowering medications; mean follow-up 7 yrs; associations with A1C
TODAY2, 2011–2020 (355) | n=677; onset age 10–17 yrs; diabetes duration <2 yrs | Consecutive elevated levels of or being prescribed lipid-lowering medication with elevated level at the same visit LDL ≥130 mg/dL TG ≥150 mg/dL | LDL Baseline: 3.4% 14-yr cumulative incidence: 32.9% TG Baseline: 18.2% 14-yr cumulative incidence: 37.4% 56.1% of participants met targets for LDL <100 mg/dL | RCT and observational follow-up; mean follow-up 10.2 yrs; associations with A1C, blood pressure, and insulin sensitivity; sex and race/ethnicity differences
Obesity and Insulin Resistance
Type 1 Diabetes
Children’s Hospital of Pittsburgh, PA, 1979–1998 (407) | n=185; onset age <19 yrs | Overweight ≥85th percentile (CDC) by chart review | Prevalence of overweight, by year of diabetes onset: ..................................[underlined: 1979–1989].....[underlined: 1990–1998] All...................................12.6%.............36.8% Age <11 yrs......................7.3%.............22.2% Age ≥11 yrs....................20.0%.............50.0% Non-Hispanic White.........2.9%..............16.6% Non-Hispanic Black........22.0%.............55.0% Ab+...................................5.1%.............24.4% Ab-..................................46.1%.............75.0% | Hospital-based; high proportion of new-onset cases are hospitalized at this hospital.
SEARCH, 2001–2004 (33) | n=3,524; onset age <20 yrs | Overweight: BMI 85th–<95th percentile (CDC) Obesity: BMI ≥95th percentile | Prevalence of overweight/obesity, by race/ethnicity: .......................................[underlined: Cases]......[underlined: NHANES] Overweight All..................................22.1%.........16.1% Non-Hispanic White......20.8%.........15.9% Non-Hispanic Black......23.4%.........14.8% Hispanic........................20.0%.........18.8% Obesity All..................................12.6%..........16.9% Non-Hispanic White......10.7%..........15.8% Non-Hispanic Black.......20.1%.........20.2% Hispanic.........................17.0%..........18.3% | Population-based; 47% of eligible youth had examination.
Barbara Davis Center, CO, 2008–2010 (474) | n=292; mean age 15.4 yrs; diabetes duration 8.8 yrs n=89 controls | Insulin sensitivity score (IS), using age, waist, A1C, and TG | Tertiles of IS score showed that T1D youth had similar cardiovascular risk factor distribution in most insulin- sensitive tertiles; linear increase in atherogenicity as IS decreased among T1D youth. | Clinic-based; ~80% of all cases in state cared for; T1D youth had lower IS score than controls (7.8 vs. 11.5, p<0.0001).
Type 2 Diabetes
Manitoba, Canada, Hospital, 1997–2002 (390) | n=99; mean age 15.3 yrs | Chart review of clinical parameters Overweight: BMI 85th–<95th percentile (CDC) Obesity: BMI ≥95th percentile | Prevalence: Overweight: 44% Obesity: 39% Overweight + obesity: 83% | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
SEARCH, 2001–2004 (33) | n=429; onset age <20 yrs | Overweight: BMI 85th–<95th percentile (CDC) Obesity: BMI ≥95th percentile | Prevalence of overweight/obesity, by race/ethnicity: ......................................[underlined: Cases].......[underlined: NHANES] Overweight All..................................10.4%.......16.1% Non-Hispanic White......13.9%.......15.9% Non-Hispanic Black........8.0%........14.8% Hispanic........................10.5%.......18.8% Obesity All...................................79.4%......16.9% Non-Hispanic White.......68.8%......15.8% Non-Hispanic Black.......91.1%.......20.2% Hispanic.........................75.0%......18.3% | Population-based; 47% of eligible youth had examination.
TODAY2, 2011–2020 (185) | n=500; onset age 10–17 yrs; diabetes duration <2 yrs | | BMI increased from baseline (reaching a plateau at 3–9 yrs), followed by a gradual decrease; overall median BMI remained in narrow range of 35.0–37.5. | RCT and observational follow-up; by the end of the study ~50% of participants were on insulin and/or metformin.

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. Conversion formulas for A1C, HDL, LDL, TC, and TG values are available in the Conversions section. A1C, glycated hemoglobin; Ab+/-, antibody positive/negative; ADA, American Diabetes Association; ApoB, apolipoprotein B; BMI, body mass index; CDC, Centers for Disease Control and Prevention; DBP, diastolic blood pressure; HDL, high-density lipoprotein; IS, insulin sensitivity score; LDL, low-density lipoprotein; NA, not available; NHANES, National Health and Nutrition Examination Survey; RCT, randomized controlled trial; SBP, systolic blood pressure; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TC, total cholesterol; TG, triglyceride; TODAY, Treatment Options for Type 2 Diabetes in Adolescents and Youth; TODAY2, long-term observational follow-up of the TODAY trial.

SOURCE: References are listed within the table.

TABLE 7.

Subclinical Cardiovascular Disease in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Arterial Stiffness
Type 1 Diabetes
Florida/Minnesota, NA (475) | n=44; age 14.6 yrs; diabetes duration 6.0 yrs n=20 controls | RH-PAT endothelial function testing | T1D had lower mean RH-PAT scores (endothelial dysfunction) than controls.
SEARCH, 2002–2006, 2008 (421) | n=1,809; onset age <20 yrs; mean diabetes duration 7.8 yrs | PWV, AIx | AIx: 7.0% PWVcf: 19.4% PWVft: 13.0% PWVcr: 12.4% | Population-based
SEARCH CVD Substudy, 2004–2005 and 2009–2011, 5 yrs apart (476) | n=535; onset age <20 yrs n=241 controls | PWV, AIx, BrachD | T1D had lower BrachD, higher AIx, and higher PWV than controls. | Population-based; associations with blood pressure; sex differences
SEARCH CVD Substudy, 2009–2011, 2 of 5 sites (427) | n=298 with both time points; onset age <20 yrs; mean diabetes duration 9.8 yrs | PWV, AIx, BrachD | PWV increased significantly over 5 yrs. | Population-based; associations with A1C, diabetes duration, obesity, blood pressure, and lipids
SEARCH CVD Substudy, 2009–2011, 2 of 5 sites (428) | n=402; onset age <20 yrs; mean diabetes duration 9.8 yrs n=206 controls | PWV, AIx, BrachD | T1D had lower BrachD, higher AIx, and higher PWV than controls. | Population-based; associations with age, adiposity, blood pressure, lipids, microalbuminuria; sex and race/ethnicity differences
SEARCH, 2011–2015 (184) | n=1,625; onset age <20 yrs; mean diabetes duration 7.9 yrs | PWV >90th percentile compared to age- and sex-matched controls | Prevalence of arterial stiffness: 11.6% | Population-based
SEARCH, 2011–2015 (323) | n=1,327; onset age <20 yrs; mean diabetes duration 7.8 yrs | PWV >90th percentile compared to age- and sex-matched controls | Prevalence of arterial stiffness: 5.2% Arterial stiffness co-occurred more frequently than expected with retinopathy and CAN. | Population-based; sex and race/ethnicity differences
SEARCH, 2011–2015 (429) | n=1,162; onset age <20 yrs; mean diabetes duration 7.8 yrs | PWV >90th percentile compared to age- and sex-matched controls | PWV did not differ between: ...Hispanic 6.18 (0.12) vs. non-Hispanic White 6.04 (0.11) ...Hispanic 6.18 (0.12) vs. non-Hispanic Black 6.36 (0.12) PWV was higher in non-Hispanic Black versus non-Hispanic White youth in all models (all p<0.001). Data are adjusted mean (SE). | Population-based: race/ethnicity differences
SEARCH, 2011–2015 and 2015–2019, 4.6 yrs apart (322) | n=949; onset age <20 yrs | PWV, AIx | Significant worsening of PWVcf and AIx over 4.6 yrs | Population-based; associations with age, diabetes duration, A1C, triglycerides, blood pressure, and physical activity; sex and race/ethnicity differences
SEARCH, 2015–2019 (436) | n=222; onset age <20 yrs; mean diabetes duration 11.2 yrs | PWV, AIx | Arterial stiffness was associated with cardiac structure and function similarly in T1D and T2D.
Type 2 Diabetes
TODAY, 2010–2011 (430) | n=453; onset age 10–17 yrs n=241 lean controls n=234 controls with obesity | PWV, AIx, BrachD PWV >90th percentile compared to age- and sex-matched lean controls | Arterial stiffness in up to 50% of participants | RCT; mean follow-up 3.9 yrs; associations with age, blood pressure, BMI, and A1C; sex and race/ethnicity differences
Cincinnati Children’s Hospital, Cincinnati, OH, 2011 (477) | n=215; age 18 yrs; diabetes duration 3.5 yrs | PWV, AIx | | Associations with age, lipids, blood pressure, and diabetes duration; race/ethnicity differences mediated by CVD risk factors
Cincinnati Children’s Hospital, Cincinnati, OH, 2011–2015 (433) | n=151 T2D n=141 healthy weight controls; n=156 controls with obesity | PWV, AIx | T2D had greater positive change in AIx and PWV compared to healthy weight controls. | Two measurements 5 yrs apart
SEARCH, 2011–2015 (184) | n=205; onset age <20 yrs; mean diabetes duration 7.9 yrs | PWV >90th percentile compared to age- and sex-matched controls | Prevalence of arterial stiffness: 47.4% | Population-based; higher prevalence in T2D compared to T1D (47.4% vs. 11.6%), absolute difference 35.9%
SEARCH, 2011–2015 (328) | n=185; onset age <20 yrs; mean diabetes duration 7.8 yrs | PWV | Participants with vs. without T2D + arterial stiffness had a worse CVD profile and lower HRV.
SEARCH, 2011–2015 and 2015–2019, 4.6 yrs apart (322) | n=210; onset age <20 yrs | PWV, AIx | Significant worsening of PWVcf and AIx over 4.6 yrs; significantly higher in T2D than T1D at both time points and in change over time | Population-based; associations with age, diabetes duration, A1C, triglycerides, blood pressure, and physical activity; sex and race/ethnicity differences
TODAY2, 2013–2014 (435) | n=388; onset age 10–17 yrs | PWV, AIx, BrachD | Arterial stiffness (composite) was associated with LV mass and DF (E/m). | RCT and observational follow-up; significant interaction with blood pressure
TODAY2, 2013–2014, 2018–2019, 5 yrs apart (327) | n=304; onset age 10–17 yrs | PWV, AIx, BrachD | Significant worsening of PWV and AIx over 5 yrs with means increasing between 14.2% and 57.8%. | RCT and observational follow-up; associations with blood pressure and A1C; no sex or race/ethnicity differences
SEARCH, 2015–2019 (436) | n=177; onset age <20 yrs; mean diabetes duration 10.3 yrs | PWV, AIx | Arterial stiffness was associated with cardiac structure and function similarly in T1D and T2D.
Carotid Intima-Media Thickness
Type 1 Diabetes
Children’s Hospital, Orange County, CA, NA (438) | n=142; mean age 16.0 yrs; diabetes duration 7.3 yrs n=87 controls; mean age 18.8 yrs | Right distal common carotid far wall IMT, in mm | ......................[underlined: All].......[underlined: Males]......[underlined: Females] Cases...........0.564.....0.572........0.558 Controls.......0.540.....0.545........0.537 | Hospital-based associations with HDL cholesterol and LDL/HDL ratio
Hospital de Especialidades, Mexico City, Mexico, NA (446) | n=52; mean age 11.8 yrs; diabetes duration 4.8 yrs n=47 controls | B mode cIMT | cIMT (mm): Cases: 0.463 Controls: 0.441 | Associations with blood pressure and LDL cholesterol
SEARCH CVD Substudy, 2004–2005 (439) | n=402; onset age <20 yrs n=206 controls | B-mode cIMT measured in common, bulb, and internal carotid, in mm | Baseline cIMT (mm): .....................[underlined: Cases]......[underlined: Controls] Common........0.449........0.450 Bulb...............0.461........0.445 Internal..........0.399........0.396 | Population-based; associations with age, adiposity, blood pressure; sex differences
SEARCH CVD Substudy, 2004–2005 and 2009–2011, 5 yrs apart (440) | n=298; onset age <20 yrs | B-mode cIMT measured in common, bulb, and internal carotid, in mm | 5-yr follow-up cIMT (mm) in cases: Common: 0.60 Bulb: 0.62 Internal: 0.55 | Population-based; associations with age and BMI; sex differences
Vancouver, Canada, NA (441) | n=24 short duration; mean age 13.4 yrs; diabetes duration 1.3 yrs n=33 long duration; mean age 14.2 yrs; diabetes duration 8.3 yrs n=29 controls | B-mode cIMT measured in common, bulb, and internal carotid, in mm | An interaction between ABPM and zBMI on cIMT was observed; in T1D with ABPM abnormalities, every 1 SD increase in zBMI was associated with a 0.030 mm increase in cIMT (95% CI 0.002–0.041, p=0.031). | ABPM abnormalities more prevalent in T1D vs. controls (57% vs 24%, respectively)
Type 2 Diabetes
Cincinnati Children’s Hospital, Cincinnati, OH, 2006–2010 (447) | n=128; age 10–24 yrs n=182 lean controls n=136 controls with obesity | Three B-mode images on left, right sides averaged for common, bulb, and internal carotid, in mm | cIMT (mm): ....................[underlined: T2D].....[underlined: Obesity].....[underlined: Lean] Common......0.54........0.50........0.52 Bulb.............0.52........0.48........0.47 Internal........0.44........0.42........0.39 | Clinic-based; associations with age, BMI, blood pressure, and cholesterol; sex and race/ethnicity differences
Cincinnati Children’s Hospital, Cincinnati, OH, 2006–2010 (448) | n=129; age 10–23 yrs; mean diabetes duration 4.4 yrs; non-insulin-requiring | Average of left, right sides for common carotid, bulb, and internal carotid, in mm | cIMT (mm): ....................[underlined: Males].....[underlined: Females] Common.......0.58..........0.52 Bulb..............0.55..........0.51 Internal.........0.48..........0.48 | Clinic-based; sex differences
Cincinnati Children’s Hospital, Cincinnati, OH, 2006–2010, 2011–2016 (433) | n=151 n=141 healthy weight controls; n=156 controls with obesity | B-mode cIMT measured in common, bulb, and internal carotid, in mm | cIMT (mm): ....................[underlined: T2D].....[underlined: Obesity].....[underlined: Healthy Wt] Common.......0.53.......0.48..............0.50 Bulb..............0.53.......0.49..............0.48 Internal.........0.43.......0.40..............0.38 | Two measurements 5 yrs apart; associations with blood pressure
Manitoba, Canada, Hospital, 2011–ongoing (450) | n=121; mean age 15.1 yrs n=34 Indigenous controls without diabetes | B-mode cIMT; strain was determined by dividing the difference in carotid internal diameter measured during peak systole and diastole from the diameter during diastole | cIMT (mm) Cases: 0.47 Controls: 0.48 cStrain (units) Cases: 0.12 Controls: 0.17 | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
Manitoba, Canada, Hospital, 2011–ongoing (451) | n=265; mean age 15.1 yrs; stratified by albuminuria status | B-mode cIMT | cIMT (mm): T2D + albuminuria: 0.46 T2D + no albuminuria: 0.48 | Clinic-based, but clinic cares for a high proportion of all cases of diabetes in the geographic region.
Coronary Artery Calcification
Type 1 Diabetes
CACTI, Denver, CO, 1997–2000 (458) | n=109; age 20–55 yrs; mean diabetes duration 23 yrs; follow-up for 2.7 yrs | Repeat EBCT for CAC; abnormal score >0; progression: ≥2.5 square root transformed calcium volume, which accounts for variability | OR for CAC progression associated with baseline: A1C ≥7.5%: 7.1 CAC: 9.7 T1D duration: 3.2 Male sex: 3.9 Age: 1.7 | Clinic-based; multivariate model; strong association of poor glycemic control; also, persons with higher BMI and more insulin dose had higher CAC risk in the same model.
EDC, Pittsburgh, PA, 1997–2005 (455) | n=222; mean age 38.1 yrs; 4-yr follow-up from first CAC | CAC progression: >2.5 increase in square root transformed Agatston score | 110 of 222 progressed (49.5%) | Hospital-based but representative of Allegheny County registry; associations with diabetes duration, baseline CAC level, BMI, non-HDL cholesterol, and albumin excretion rate; no associations with A1C
CACTI, Denver, CO, 2000–2002 (457) | n=656; age 20–55 yrs; mean diabetes duration 23 yrs n=764 controls | EBCT for CAC; abnormal score >0; insulin resistance by equation, including waist/hip ratio, A1C, and hypertension | OR for CAC prevalence in T1D vs. controls Males: 2.1 Females: 3.6 Prevalence (in age 20–29 yrs) Males: 24% Females: 14% | Clinic-based; insulin resistance, lipids, and A1C explained most of the excess CAC in T1D women.
Morristown, NJ, 2002 (454) | n=101; age 17–29 yrs; ≥5 yrs diabetes duration | Forty 3 mm slices by EBCT; positive: CAC scores >0 | Prevalence of positive CAC: All: 10.9% Males: 15.1% Females: 6.3% | Clinic-based; mean score among positives was 12.5; smokers had fivefold higher prevalence of CAC; no associations with A1C, diabetes duration, BMI, or microalbuminuria.
Type 2 Diabetes
No data

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. A1C, glycated hemoglobin; ABPM, ambulatory blood pressure monitoring; AIx, augmentation index; BMI, body mass index; BrachD, brachial distensibility; CAC, coronary artery calcification; CACTI, Coronary Artery Calcification in Type 1 Diabetes (CACTI) study; CAN, cardiovascular autonomic neuropathy; CI, confidence interval; cIMT, carotid intima-media thickness; CVD, cardiovascular disease; DF, diastolic function; EBCT, electron beam computed tomography; EDC, Pittsburgh Epidemiology of Diabetes Complications Study; HDL, high-density lipoprotein; HRV, heart rate variability; IMT, intima-media thickness; LDL, low-density lipoprotein; LV, left ventricular; NA, not available; OR, odds ratio; PWV(cf/cr/ft), pulse wave velocity (carotid-femoral/carotid-radial/finger-toe); RCT, randomized controlled trial; RH-PAT, reactive hyperemia peripheral arterial tonometry; SD, standard deviation; SE, standard error; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes; TODAY, Treatment Options for Type 2 Diabetes in Adolescents and Youth; TODAY2, long-term observational follow-up of the TODAY trial.

SOURCE: References are listed within the table.

TABLE 8.

Mortality in Youth With Diabetes

STUDY OR SITE, YEARS OF DATA COLLECTION (REF.) | POPULATION | METHOD | OUTCOME | COMMENTS
Type 1 Diabetes
SEARCH, 2002–2015 (461,478) | n=14,721 with T1D; onset age <20 yrs in 2002–2015; follow-up through 2017 | Vital status by local confirmation and National Death Index; cause of death from ICD-10 codes | MR at 8.7 yrs median yrs of follow-up: All: 103.0 Sex Male: 110.6 Female: 94.7 Race/ethnicity Non-Hispanic White: 98.9 Non-Hispanic Black: 140.2 Hispanic: 106.8 | Population-based; 97.9% ascertainment of vital status; youth age <25 (<15, 15–19 and 20–24 yrs); all race/ethnicity groups except non-Hispanic White youth and both males and females had higher mortality rates than the underlying U.S. population
Type 2 Diabetes
SEARCH, 2002–2015 (461,478) | n=4,141 with T2D; onset age <20 yrs in 2002–2015; follow-up through 2017 | Vital status by local confirmation and National Death Index; cause of death from ICD-10 codes | MR at 7.8 median yrs of follow-up: All: 161.5 Sex Male: 258.4 Female: 100.5 Race/ethnicity Non-Hispanic White: 106.6 Non-Hispanic Black: 215.0 Hispanic: 116.3 | Population-based; 97.9% ascertainment of vital status; youth age <25 (<15, 15–19 and 20–24 yrs); non-Hispanic White and Hispanic youth and females had higher mortality rates than the underlying U.S. population
All Types of Diabetes
U.S. Census, 2000–2014 (463) | Age 1–19 yrs | Annual mortality rates from diabetes as underlying cause on death certificate | Rates per million by race/ethnicity: ..................................[underlined: 2000–2002].....[underlined: 2012–2014] All....................................1.15.............0.97 Non-Hispanic White.........1.01..............0.92 Non-Hispanic Black.........2.39..............2.04 Hispanic............................0.65..............0.61 | Highest rates among non-Hispanic Black youth; lowest rates among Hispanic youth

The “Comments” column provides additional information on study design, subgroup comparisons, and risk factor associations. ICD-10, International Classification of Diseases, Tenth Revision; MR, mortality rate/10^5^ person-yrs; SEARCH, SEARCH for Diabetes in Youth study; T1D, type 1 diabetes; T2D, type 2 diabetes.

SOURCE: References are listed within the table.