# External Reviewers

- Mohammed K. Ali
- David C. Aron
- Kiran Bambha
- Linda Barbour
- Roy Beck
- Dorothy J. Becker
- Peter H. Bennett
- Rudy Bilous
- Knut Borch-Johnsen
- Andrew J. M. Boulton
- Donald W. Bowden
- Barbara A. Bowman
- Frederick L. Brancati
- Elizabeth Osborne Buschur
- Tim Byers
- Mercedes Carnethon
- Emily Chew
- J. Quentin Clemens
- Tina Costacou
- Donald Coustan
- Dana Dabelea
- Samuel Dagogo-Jack
- Mayer Davidson
- James E. Everhart
- Roberto J. Fajardo
- Denice Feig
- Vivian Fonseca
- Robert N. Frank
- Saul M. Genuth
- Stephen E. Gitelman
- Dale Glasser
- Mugdha N. Gokhale
- Ronald B. Goldberg
- Sherita Hill Golden
- Rebecca Gottesman
- Richard W. Grant
- Siri Atma W. Greeley
- Edward W. Gregg
- Jeffrey B. Halter
- Richard F. Hamman
- Craig L. Hanis
- Morey W. Haymond
- William H. Herman
- Kevan Herold
- Frank B. Hu
- Elbert S. Huang
- Debra E. Irwin
- Rita Rastogi Kalyani
- Alka Kanaya
- Catherine Kim
- Abbas Kitabchi
- Ayman Koteish
- Lori Laffel
- Lenore J. Launer
- Kevin V. Lemley
- Åke Lernmark
- Terri H. Lipman
- Benjamin A. Lipsky
- Rebecca B. Lipton
- Peter Liu
- Rohit Loomba
- José A. Luchsinger
- David Maahs
- Farid Mahmud
- David J. Margolis
- Sally M. Marshall
- Chantal Mathieu
- Briana Mezuk
- Andrew Muir
- Medha Munshi
- Karin M. Nelson
- Jerry Nepom
- Gregory A. Nichols
- Janelle A. Noble
- Patrick J. O’Connor
- Cynthia L. Ogden
- Trevor J. Orchard
- Henry P. Parkman
- Mark A. Pereira
- Louis Philipson
- Flemming Pociot
- Leonard Pogach
- Michel Polak
- Alberto Pugliese
- Lawrence Rand
- Robert E. Ratner
- Andrew G. Renehan
- Mishaela R. Rubin
- Constance E. Ruhl
- Christopher Ryan
- Peter Savage
- Sharon H. Saydah
- Desmond A. Schatz
- Frank A. J. L. Scheer
- Elizabeth Selvin
- Jonathan Shaw
- Alan R. Shuldiner
- Andrea Steck
- Marie-Pierre St-Onge
- Kingman Strohl
- Elsa S. Strotmeyer
- Til Stürmer
- Solomon Tesfaye
- Leslie Tinker
- Paula M. Trief
- Jaakko Tuomilehto
- Katherine R. Tuttle
- Nigel Unwin
- Kendra Vehik
- Aristidis Veves
- Stefano Volpato
- Matthias von Herrath
- Julie Wagner
- Nick Wareham
- Deborah Wexler
- Diane Wherrett
- Yun Kwok Wing
- Barton Wise
- Kenneth P. Wright
- Kristine Yaffe
- Ping Zhang
- Xuanping Zhang
- Anette-Gabriele Ziegler