# Steering Committee

- Catherine C. Cowie, PhD, MPH, Senior Advisor and Director for Diabetes Epidemiology, National Institute of Diabetes and Digestive and Kidney Diseases, National Institutes of Health, Bethesda, MD
- Sarah Stark Casagrande, PhD, Senior Research Analyst, Social & Scientific Systems, Inc., Silver Spring, MD
- Michelle A. Cissell, PhD, Science Writer/Editor, Chicago, IL
- Mark S. Eberhardt, PhD, Epidemiologist, Division of Health and Nutrition Examination Surveys, National Center for Health Statistics, Centers for Disease Control and Prevention, Hyattsville, MD
- Edward W. Gregg, PhD, Chief, Epidemiology and Statistics Branch, Division of Diabetes Translation, Centers for Disease Control and Prevention, Atlanta, GA
- William C. Knowler, MD, DrPH, Chief, Diabetes Epidemiology and Clinical Research Section, National Institute of Diabetes and Digestive and Kidney Diseases, National Institutes of Health, Phoenix, AZ
- James B. Meigs, MD, MPH, Professor of Medicine, Harvard Medical School, and Physician, Division of General Internal Medicine, Department of Medicine, Massachusetts General Hospital, Boston, MA
- Andy Menke, PhD, Senior Research Analyst, Social & Scientific Systems, Inc., Silver Spring, MD