# CHAPTER 37 Prevention of Type 1 Diabetes

## Summary

Type 1 diabetes is a progressive disease. There is a genetic predisposition to type 1 diabetes, particularly conferred by alleles present within the major histocompatibility complex (HLA region) on the short arm of chromosome six. It is thought that in susceptible individuals, an environmental trigger initiates an immune response. Immune infiltration into pancreatic islets results in beta cell damage, impairment of beta cell function, and potential destruction of beta cells. One would expect that if type 1 diabetes is an immunologically mediated disease, then immune intervention should alter the natural history of the disease and potentially abrogate the clinical syndrome.

Intervention trials have been conducted at a number of stages of the disease process. Primary prevention trials have been conducted in individuals with a genetic predisposition who have not yet developed immunologic markers (“Pre-Stage 1”). Secondary prevention trials have been conducted in individuals with two or more diabetes-related autoantibodies, either during Stage 1 of type 1 diabetes (normal metabolic function) or Stage 2 of type 1 diabetes (abnormal metabolic function). Intervention trials, also called tertiary prevention trials, have been conducted in individuals with Stage 3 of type 1 diabetes (clinical hyperglycemia), usually shortly after clinical onset of disease.

This chapter provides brief summaries of the randomized controlled clinical trials that have been conducted and also mentions some non-randomized pilot studies. Unfortunately, none of the primary or secondary prevention trials have clearly arrested the disease process. Some tertiary intervention trials have demonstrated improved beta cell function, at least for some period of time, after which beta cell function has generally declined in parallel to that in the respective control group. This could be a consequence of most studies focusing on only a single immunologic mechanism; whereas, what may be required are studies that deal with multiple immunologic mechanisms, including attempting to improve regulatory immunity, while also addressing beta cell function by including interventions that improve beta cell health.

## Introduction

Type 1 diabetes is a slowly progressive disease, with a genetic predisposition, where a putative environmental trigger initiates an immune response that results in pancreatic islet beta cell damage, impairment of beta cell function, and destruction of beta cells (1,2,3). Although the initial characterization suggested a slow, linear progression of disease (Figure 37.1) (1), more recent thought is that there is more variability in the progression, perhaps with waxing and waning or with intermittent immune attacks (3). Moreover, the disease may be a consequence of imbalance between the immune system and the ability of the pancreatic beta cell to withstand attack (4).

A genetic basis for the disease in association with human leukocyte antigen (HLA) was first described in the early 1970s (5). Subsequently, that relationship has been extensively characterized (6,7,8,9), with both Class II (9,10) and Class I HLA (11) contributing to genetic susceptibility, and even the identification of protective HLA haplotypes (12). Although multiple other potential genes have been identified as possible contributors to type 1 diabetes (13,14), the HLA region remains the major contributor to genetic predisposition (15). Indeed, based on a study of the general population of Denver newborns, children born with the high-risk genotype HLA-DR3/4-DQ8 comprise almost 50% of children who develop anti-islet autoimmunity by age 5 years (16). In addition, the cumulative burden of non-major histocompatibility complex (MHC) susceptibility genes may play a role in determining the rate of disease progression. Genetic factors associated with type 1 diabetes are described in detail in Chapter 12 Genetics of Type 1 Diabetes.

In genetically susceptible individuals, the disease process eventuating in type 1 diabetes likely is initiated by an environmental trigger (17,18). It is unclear whether such a trigger is an infectious agent, such as an enterovirus, a dietary factor, alteration of the intestinal microbiome, or some other factor. Moreover, the association between environmental factors and the course of the disease is complicated by observations that not only initiation of the disease process, but also the rate of progression to clinical onset, may be affected by environmental determinants and that metabolic decompensation at disease onset may be a consequence of another unrelated or nonspecific environmental event. Ongoing observational cohort studies, such as The Environmental Determinants of Diabetes in the Young (TEDDY) study (19,20), are designed to ascertain environmental determinants that may trigger islet autoimmunity and either speed up or slow down the progression to clinical onset in subjects with persistent islet autoimmunity. Please see Chapter 11 Risk Factors for Type 1 Diabetes for more discussion of putative environmental triggers of type 1 diabetes.

The type 1 diabetes immune response is initiated by antigen presentation and then mediated by T lymphocytes (21,22), resulting in a lymphocytic inflammatory response in pancreatic islets that has been called insulitis (23). It appears to involve an autoreactive response by both effector CD4 (24) and cytotoxic CD8 (25) T lymphocytes. These have the capacity to mediate damage both via cytokine effects (possibly involving such cytokines as interleukin-1 [IL-1] and tumor necrosis factor alpha [TNF-α]) or direct cytotoxic T lymphocyte-mediated lysis. This initial immune response, with continued lysis, creates the potential of a vicious cycle of inflammation, which also may engender secondary and tertiary immune responses that contribute to the impairment of beta cell function and potential destruction of beta cells (3,4,21). This insidious process evolves over a variable amount of time—even many years in some individuals. The eventual overt manifestation of clinical symptoms becomes apparent only when most beta cells have lost function and many may have been destroyed.

The initial laboratory manifestation of this beta cell injury is seroconversion, i.e., the appearance of diabetes-related autoantibodies. These antibodies are generally thought not to mediate beta cell injury but rather to be markers of such injury. Diabetes-related autoantibodies were first described in the early 1970s, when islet cell antibodies (ICA) were identified by immunofluorescence (26). Subsequently, additional antibodies were identified with specific antigen targets, including insulin autoantibodies (IAA), antibodies to glutamic acid decarboxylase (GAD), antibodies to an aborted tyrosine phosphatase, which has been called islet antibody-2 (IA2), and antibodies to the zinc transporter (ZnT8) (27), all of which are components of beta cells.

FIGURE 37.1 Natural History of Type 1 Diabetes, 1986

A model of the natural history of type 1 diabetes, as proposed by Dr. George S. Eisenbarth in 1986. GAD65, glutamic acid decarboxylase 65 kD; IA2Ab, islet antibody-2; IAA, insulin autoantibodies; ICA, islet cell antibodies; IVGTT, intravenous glucose tolerance test; OGTT, oral glucose tolerance test; ZnT8, zinc transporter 8.

Flow chart showing a proposed model of the natural history of type 1 diabetes from genetic predisposition, to insulitis beta-cell injury, to prediabetes, then diabetes.

SOURCE: Adapted from Reference 1, copyright © 1986 Massachusetts Medical Society, reprinted with permission

FIGURE 37.2 Stages of Type 1 Diabetes, 2015

A model of type 1 diabetes staging, as proposed in a joint scientific statement of the JDRF, Endocrine Society, and American Diabetes Association in 2015.

Flow chart showing the stages of type 1 diabetes from genetic predisposition, to autoantibodies, to dysglycemia, and finally symptomatic diabetes.

SOURCE: Adapted from Reference 32, copyright © 2015 American Diabetes Association, reprinted with permission from the American Diabetes Association

Seroconversion is an important marker of the type 1 diabetes disease process. Indeed, in longitudinal studies of birth cohorts identified by genetic screening, such as DAISY (Diabetes AutoImmunity Study in the Young) (28), BABYDIAB (29), and DIPP (DIabetes Prediction and Prevention study) (30), if two or more antibodies appear, there is near certain progression to type 1 diabetes over the next two decades (31). This finding has led to a new classification of type 1 diabetes (Figure 37.2), in which the presence of two or more antibodies defines Stage 1 of type 1 diabetes (32).

During further evolution of the disease, progressive metabolic changes are observable (33). Lack of beta cell sensitivity to glucose, i.e., failure of the beta cell to recognize glucose and appropriately secrete insulin, is an early defect (34), similar to that seen in type 2 diabetes (35). This may be manifested by loss of first phase insulin response to intravenous glucose (36) and dysglycemia (abnormal glucose levels not reaching the threshold for clinical diagnosis), which defines Stage 2 type 1 diabetes. Ultimately, there is progression to clinical type 1 diabetes (37), now also called Stage 3 (32). A risk score, taking into account several of these metabolic changes, has been developed (38) and validated (39). After the clinical onset of type 1 diabetes, there is further progressive decline of beta cell function (40).

One would expect that if type 1 diabetes is an immunologically mediated disease, then immune intervention should alter the natural history of the disease and potentially abrogate the clinical syndrome. This has certainly been the case in animal models of type 1 diabetes (41,42,43). The first reported attempt at immune intervention in type 1 diabetes was in the late 1970s in a handful of subjects (44). In the 1980s, a number of small trials were conducted with a variety of immunologic agents (45,46). Since then, initially stimulated by a provocative pilot study with cyclosporine (47), a large number of studies have been conducted, mostly in recent-onset type 1 diabetes in an attempt to interdict the disease process and preserve beta cell function (48,49). A few studies have been conducted prior to any evidence of autoimmunity (primary prevention) or after the development of diabetes-related autoantibodies (secondary prevention) (50). The goal of such primary and secondary interventions is to arrest the immune process and, thus, prevent or delay clinical disease.

Table 37.1 lists both completed and ongoing primary and secondary prevention trials. Table 37.2 lists a large number of contemporary intervention trials in subjects with clinical Stage 3 type 1 diabetes, mostly in recent-onset subjects, but some in established disease. Most studies listed are randomized controlled clinical trials, although a few pilot studies of significance are included.

## Primary Prevention Trials

Primary prevention trials (Table 37.1) have been conducted in birth cohorts identified by genetic screening, with the interventions initiated at a time when there are neither signs of autoimmunity nor metabolic impairment. Since there is uncertainty as to whether those infants identified by genetic screening will progress to type 1 diabetes, any interventions tested must be extremely safe. As a consequence, virtually all primary prevention trials to date have involved dietary interventions directed at putative environmental triggers of type 1 diabetes (51,52,53,54,55,56).

A meta-analysis had demonstrated a correlation between onset of type 1 diabetes and either early introduction of cow’s milk formula or a short period of breastfeeding (57). Consequently, two studies evaluated whether at the time of weaning, replacement of breast milk with a formula based on casein hydrolysate rather than conventional cow’s milk-based formula could reduce the development of autoimmunity (51,52). Eligible infants had HLA-conferred susceptibility to type 1 diabetes and at least one family member with type 1 diabetes. A pilot study in Finland enrolled 230 infants (51). The investigators reported that the group assigned to casein hydrolysate formula had a reduced risk of development of beta cell autoimmunity (appearance of one or more antibodies) (hazard ratio [HR] 0.54, 95% confidence interval [CI] 0.29–0.95; HR adjusted for observed difference in duration of exposure to study formula 0.51, 95% CI 0.28–0.91) (51). The larger Trial to Reduce IDDM in the Genetically at Risk (TRIGR) study, a multinational trial involving 77 centers in 15 countries, registered over 5,000 newborns and randomized 2,159 newborns with risk genotypes (approximately 45% of those screened) (52). After 7 years, the TRIGR Study Group found no difference in the rate of appearance of diabetes autoantibodies (52). In the group assigned to casein hydrolysate formula, 13.4% had two or more islet autoantibodies versus 11.4% among those randomized to the conventional formula (unadjusted HR 1.21, 95% CI 0.94–1.54). When the hazard ratio was adjusted for HLA risk, duration of breastfeeding, vitamin D use, study formula duration and consumption, and region of the world, it was 1.23 (95% CI 0.96–1.58). Nonetheless, TRIGR is continuing follow-up because it was designed with a primary outcome of the development of type 1 diabetes by age 10 years.

To evaluate whether bovine insulin might be the component of cow’s milk that serves as a trigger for type 1 diabetes, the Finnish Dietary Intervention Trial for the Prevention of Type 1 Diabetes (FINDIA) compared three formulas: cow’s milk formula (control), whey-based hydrolyzed formula, or whey-based FINDIA formula essentially free of bovine insulin, whenever breast milk was not available during the first 6 months of life (53). Of 5,003 infants screened, 1,113 were found eligible, 1,104 were randomized, and 908 provided at least one follow-up sample. By age 3 years, the group assigned to the FINDIA formula had a reduced risk of development of beta cell autoimmunity, defined as the appearance of one or more antibodies (in the intention-to-treat analysis, odds ratio [OR] 0.39, 95% CI 0.17–0.91, p=0.03; in the actual treatment-received analysis, OR 0.23, 95% CI 0.08–0.69, p<0.01, in the FINDIA group when compared with the cow’s milk formula group) (53).

TABLE 37.1 Trials for Primary and Secondary Prevention of Type 1 Diabetes

STUDY NAME (REF.) | INTERVENTION | NUMBER RANDOMIZED | ACTIVE: PLACEBO | AGE RANGE (YEARS) | PRIMARY OUTCOME | HAZARD RATIO (95% CI) | P-VALUE
Primary prevention studies—completed
Finnish TRIGR Pilot (51) | Casein hydrolysate formula | 230 | 1:1 | birth | Autoantibodies | 0.54 (0.29–0.95) | 0.005
TRIGR (52) | Casein hydrolysate formula | 2,159 | 1:1 | birth | Autoantibodies | 1.21 (0.94–1.54) | 0.14
FINDIA (53) | Insulin-free whey based formula | 1,104 | 1:1:1 | birth | Autoantibodies | OR 0.39 (0.17–0.91) | 0.03
BABYDIET (54) | Gluten-free diet | 150 | 1:1 | birth | Autoantibodies | 1.3 (0.6–3.0) | 0.6
NIP Pilot Trial (55) | Docosahexaenoic acid | 98 | 1:1 | birth | Cytokines | | NS
Canadian Vitamin D Pilot Trial (56) | Supplemental vitamin D | 9 | 1:1 | birth | 25-OH-D levels | | NA
Pre-POINT (59) | Oral insulin | 25 | 1.5:1 | 2–7 | Safety | No issues | NA
Primary prevention studies—ongoing^*^
TRIGR (52) | Casein hydrolysate formula | 2,159 | 1:1 | birth | Diagnosis of type 1 diabetes | ^†^ | ^†^
Secondary prevention studies—completed
DENIS (61) | Nicotinamide | 55 | 1:1 | 3–12 | Diagnosis of type 1 diabetes | 0.79 (0.25–3.38) | 0.97
ENDIT (62) | Nicotinamide | 552 | 1:1 | 3–40 | Diagnosis of type 1 diabetes | 1.07 (0.78–1.45) | 0.69
DPT-1 Parenteral Insulin (63) | Injected insulin | 339 | 1:1 | 4–45 | Diagnosis of type 1 diabetes | 0.96 (0.69–1.34) | 0.80
DPT-1 Oral Insulin (64,65,66) | Oral insulin | 372 | 1:1 | 3–45 | Diagnosis of type 1 diabetes | 0.76 (0.51–1.14) | 0.189
Belgian Parenteral Insulin (67) | Injected insulin | 50 | 1:1 | 5–40 | Diagnosis of type 1 diabetes | NA | 0.97
DIPP birth cohort (68) | Nasal insulin | 224 | 1:1 | 1–5 | Diagnosis of type 1 diabetes | 1.14 (0.73–1.77) | 0.55
DIPP sibling cohort (68) | Nasal insulin | 40 | 1:1 | 4–11 | Diagnosis of type 1 diabetes | 1.93 (0.56–6.77) | 0.30
INIT-1 Pilot Safety Study (69) | Nasal insulin | 38 | Cross-over | 5–33 | Safety | NA | NA
Secondary prevention studies—ongoing^*^
INIT-II (70) | Nasal insulin | 110 | 1:1 | 4–30 | Diagnosis of type 1 diabetes | ^†^ | ^†^
TrialNet Oral Insulin (71) | Oral insulin | 393 | 1:1 | 3–45 | Diagnosis of type 1 diabetes | ^†^ | ^†^
DIAPREV-IT (72) | Glutamic acid decarboxylase | 50 | 1:1 | 4–18 | Diagnosis of type 1 diabetes | ^†^ | ^†^
TrialNet Teplizumab (73) | Anti CD3 - Teplizumab | 71 | 1:1 | 8–45 | Diagnosis of type 1 diabetes | ^†^ | ^†^
TrialNet Abatacept (74) | Abatacept | Enrolling – 132 of 206^*^ | 1:1 | 6–45 | Diagnosis of type 1 diabetes | ^†^ | ^†^

25-OH-D, 25-hydroxyvitamin D; CI, confidence interval; DENIS, German (Deutsch) Nicotinamide Diabetes Intervention Study; DIAPREV-IT, Diabetes Prevention - Immune Tolerance study; DIPP, Diabetes Prediction and Prevention Study; DPT-1, Diabetes Prevention Trial-Type 1; ENDIT, European Nicotinamide Diabetes Intervention Trial; FINDIA, Finnish Dietary Intervention Trial for the Prevention of Type 1 Diabetes; INIT, Intranasal Insulin Trial; NA, not applicable; NIP, Nutritional Intervention to Prevent Type 1 Diabetes; NS, nonsignificant; OR, odds ratio; Pre-POINT, Primary Oral Insulin Therapy Study; TRIGR, Trial to Reduce the Incidence of Diabetes in the Genetically at Risk.

* As of January 2017

† Data are not available as of January 2017.

SOURCE: References are listed within the table.

The BABYDIET study, a randomized controlled trial, evaluated whether delayed exposure to gluten reduces the risk of diabetes autoimmunity (54). The rationale for the study was based on the investigators’ earlier observation of increased risk of islet autoimmunity in children who are exposed to gluten early in life (58). The trial randomized 150 infants with a first-degree relative with type 1 diabetes and an HLA genotype consistent with type 1 diabetes risk. They were assigned either to first gluten exposure at age 6 months (control group) or at age 12 months (late-exposure group) and were followed every 3 months until age 3 years and yearly thereafter. BABYDIET found that delaying gluten exposure until the age of 12 months is safe but does not substantially reduce the risk for islet autoimmunity (3-year risk: 12% vs. 13%, p=0.6) (54).

The TrialNet Nutritional Intervention to Prevent (NIP) Type 1 Diabetes Pilot Trial assessed the feasibility of implementing a study to determine the effect of nutritional supplements with the omega-3 fatty acid docosahexaenoic acid (DHA), which has anti-inflammatory effects, during the last trimester of pregnancy and the first few years of life (55). NIP found that supplementation of infant diets with DHA was safe and resulted in an increased level of DHA in infant erythrocytes but did not find consistent changes in inflammatory cytokines (55).

Based on putative observations that vitamin D may be protective against type 1 diabetes, a group of Canadian investigators showed in a small pilot study that it was possible to recruit babies from the general population for identification of HLA-associated risk status followed by enrollment by age 1 month to a randomized controlled prevention trial of vitamin D supplementation (56). Therefore, they have proposed a nationwide study (in Canada) to evaluate the hypothesis that vitamin D supplementation can decrease the risk of islet autoimmunity and type 1 diabetes.

The Primary Oral Insulin Therapy (Pre-POINT) study was a pilot safety study of the use of oral insulin in children age 2–7 years at risk of developing type 1 diabetes (59). The study found that daily oral administration of 67.5 mg insulin is safe and can actively engage the immune system with features of immune regulation in children who are genetically at risk of developing type 1 diabetes. Consequently, a larger randomized controlled trial has been initiated (60).

It would seem desirable to conduct more studies in those with genetic predisposition, particularly if a safe vaccine-type approach can be studied. This might involve an antigen-based vaccine (such as that used in the Pre-POINT study) or a vaccine directed against potential viral triggers of disease. In order to conduct such trials, it will be necessary to screen various populations at or shortly after birth, looking for high-risk genetic predisposition. Theoretically, if such trials resulted in prevention of type 1 diabetes, this would change public health practice, leading to routine screening at birth for high genetic risk of type 1 diabetes. Further, if the intervention were totally safe, it could ultimately be included in routine neonatal or infant vaccination programs.

## Secondary Prevention Trials

Secondary prevention trials (Table 37.1) are those conducted in individuals with Stage 1 (autoantibodies alone) or Stage 2 type 1 diabetes (autoantibodies and metabolic dysfunction) (Figure 37.2) (32). Most of these studies have been conducted in individuals, generally first- or second-degree relatives of people with type 1 diabetes, who initially have been identified by screening for diabetes-associated autoantibodies. Because not all of those with antibodies will progress to type 1 diabetes, selection of interventions to be tested has been done cautiously. Indeed, all completed secondary prevention studies have used either nicotinamide (a water soluble vitamin [B6] derived from nicotinic acid) or insulin given in one form or another (61,62,63,64,65,66,67,68,69). Ongoing secondary prevention trials are either antigen-based—using insulin (nasal (70) or oral (71)) or GAD (72)—or use immunomodulatory therapies that have previously been found to be relatively safe and with beneficial effects on beta cell function in tertiary prevention studies in recent-onset type 1 diabetes, namely teplizumab (73) and abatacept (74).

### Nicotinamide Trials

Nicotinamide, a water-soluble vitamin, had been shown to prevent diabetes in animal models and was asserted to have beneficial effect in school children. Consequently, two studies evaluated the effects of nicotinamide in at-risk relatives of individuals with type 1 diabetes: the German (Deutsch) Nicotinamide Diabetes Intervention Study (DENIS) (61) and the European Nicotinamide Diabetes Intervention Trial (ENDIT) (62). Both were randomized placebo-controlled trials. DENIS randomized 55 relatives age 3–12 years and used a sequential interim analysis design, which provided a 10% probability of a type II error against a reduction of the cumulative diabetes incidence at 3 years from 30% to 6% by nicotinamide. The trial was terminated, after 11 cases of diabetes, when it failed to achieve that endpoint (p=0.97) (61). ENDIT screened over 35,000 relatives age 3–40 years and randomized 552 individuals to nicotinamide or placebo. By confining recruitment to ICA-positive, first-degree relatives of individuals in whom type 1 diabetes had onset at age <20 years, the relatives who screened positive were projected to have a 5-year risk of type 1 diabetes of 40%. During 4 years of follow-up, the rate of development of type 1 diabetes was nearly identical in both the nicotinamide and placebo groups, with an unadjusted hazard ratio of 1.07 (95% CI 0.78–1.45, p=0.69) (62). Thus, in these two studies, nicotinamide failed to delay the development of type 1 diabetes.

### Insulin Trials

The Diabetes Prevention Trial-Type 1 (DPT-1) Study Group conducted two studies concomitantly: (1) the DPT-1 Parenteral Insulin Trial (63) evaluated injected (parenteral) insulin in individuals with a projected 5-year risk of type 1 diabetes of at least 50% (who had Stage 2 type 1 diabetes) and (2) the DPT-1 Oral Insulin Trial (64) evaluated oral insulin in individuals with a projected 5-year risk of type 1 diabetes of 25%–50% (who had Stage 1 type 1 diabetes). DPT-1 screened over 100,000 relatives of patients with type 1 diabetes for ICA by immunofluorescence and randomized 339 and 372 subjects, respectively, in the two trials.

Eligibility for the DPT-1 Parenteral Insulin Trial required, in addition to antibodies, evidence of decreased metabolic function, manifested by either reduced first phase insulin response to intravenous glucose or glucose intolerance during an oral glucose tolerance test, thus meeting the criteria for Stage 2 type 1 diabetes. The experimental intervention was two daily injections of long-acting ultralente insulin, plus a 96-hour continuous intravenous insulin infusion at baseline and annually thereafter. The randomized control group was closely observed but did not receive placebo. The rate of development of diabetes was the same in both the treated group and the control group (HR 0.96, 95% CI 0.69–1.34, p=0.80) (63). The DPT-1 Parenteral Insulin Trial found that the actual 5-year rate of developing type 1 diabetes was 65%, greater than the projected rate of at least 50%.

Eligibility for the DPT-1 Oral Insulin Trial required, in addition to ICA, IAA, intact first phase insulin response to intravenous glucose, and normal glucose tolerance, thus meeting the criteria for Stage 1 type 1 diabetes. Randomized subjects received either oral insulin or matched placebo taken daily. The rate of development of diabetes was the same in both groups (HR 0.76, 95% CI 0.51–1.14, p=0.189) (64). The DPT-1 Oral Insulin Trial found that the actual 5-year rate of developing type 1 diabetes was 35%, within the projected range of 25%–50%. In a post hoc analysis, a subgroup (individuals with higher IAA titers at baseline) was identified in which oral insulin appeared to have a beneficial effect. This subgroup had a projected delay of 4.5–5 years in onset of type 1 diabetes if baseline IAA titer was >80 nU/mL (64) and a projected delay of 10 years if baseline IAA titer was >300 nU/mL (65). Further follow-up of the DPT-1 oral insulin cohort showed that effects were maintained after administration of oral insulin was ceased (66). Because the subgroup with a potential beneficial effect was identified in a post hoc analysis, an ongoing trial conducted by Type 1 Diabetes TrialNet is examining oral insulin in subjects similar to those in the subgroup with higher titer IAA (71).

The Belgian Diabetes Registry also evaluated whether parenteral insulin might delay the development of type 1 diabetes (67). In this study, the experimental group received regular insulin twice daily before the most carbohydrate-rich meals, and the randomized control group was closely observed but did not receive placebo. Fifty subjects were randomized—25 each to treatment and control. Eligible subjects were age 5–40 years, with IA2 antibodies and normal oral glucose tolerance, thus meeting the criteria of Stage 1 type 1 diabetes. There was no difference in diabetes-free survival between the two groups (p=0.97), with 5-year progression of 44% in the treated group and 49% in the control group.

The DIPP study was conducted in Finland among newborns from the general population (i.e., without relatives with type 1 diabetes) with high-risk HLA-DQB1 susceptibility alleles for type 1 diabetes (68). Cord blood samples from 116,720 consecutively born infants were screened, which identified 17,397 with high or moderate genetic risk, of whom 10,577 participated in a prospective study with serial follow-up for presence of diabetes autoantibodies. The intervention study required at least two antibodies in two consecutive samples (Stage 1 type 1 diabetes); of 328 subjects who met that criteria, 224 were randomized to receive either intranasal insulin or placebo. DIPP also screened siblings of those infants and followed those siblings who also had increased genetic risk; of 52 siblings who met enrollment criteria, 40 were randomized to receive intranasal insulin or placebo. During follow-up, within each of the cohorts (infants and siblings), the rate of progression to type 1 diabetes was the same in the intranasal insulin group and the placebo group (68).

Another study, conducted in Australia, the Intranasal Insulin Trial (INIT 1), used a double-blind crossover design to evaluate safety of intranasal insulin (69). The study included 38 subjects at risk of type 1 diabetes, who were treated with either intranasal insulin or placebo, daily for 10 days and then 2 days per week for 6 months, after which they were crossed over to the other treatment. There was no acceleration of onset of type 1 diabetes nor were there other adverse outcomes. Intranasal insulin was associated with an increase in antibody and a decrease in T cell responses to insulin. Since there were no safety issues, the ongoing Intranasal Insulin Trial-II (INIT II), under the auspices of the Diabetes Vaccine Development Centre (DVDC) in Australia, is evaluating whether intranasal insulin can delay or prevent the onset of type 1 diabetes (70).

### Other Ongoing Secondary Prevention Trials

As noted in Table 37.1, other ongoing secondary prevention trials include the Diabetes Prevention - Immune Tolerance study (DIAPREV-IT) with a GAD vaccine (72) and Type 1 Diabetes TrialNet studies using teplizumab (73) and abatacept (74). The enrollment criteria for three ongoing TrialNet studies are different. Eligibility for the TrialNet oral insulin study (71) requires at least two antibodies, one of which is IAA, intact first phase insulin response to intravenous glucose, and normal glucose tolerance. Eligibility for the TrialNet abatacept study (74) requires at least two antibodies, one of which is not IAA, and normal glucose tolerance. Eligibility for the TrialNet teplizumab study (73) requires at least one antibody and dysglycemia during an oral glucose tolerance test.

### Screening and Enrollment for Secondary Prevention Trials

Secondary prevention trials involve screening of relatives of people with type 1 diabetes and enrollment of those with early markers of disease, either autoantibodies alone (Stage 1) or autoantibodies and metabolic dysfunction (Stage 2). In cross-sectional screening of relatives for autoantibodies in DPT-1 and TrialNet, <5% of relatives are found to have autoantibodies. Although this rate is tenfold to twentyfold higher than would be seen in the general population of the United States, it still means that to enroll secondary prevention trials, large numbers of subjects need to be screened. For example, DPT-1 screened over 100,000 relatives to enroll a total of 711 subjects in the two arms of that study (parenteral insulin and oral insulin).

## Tertiary Prevention Trials

Tertiary prevention trials (Table 37.2) have been conducted in subjects with Stage 3 clinical type 1 diabetes (i.e., classic symptomatic type 1 diabetes requiring insulin therapy) (Figure 37.2) (32), mostly recent onset, but some in established disease. As noted, there were many early pilot trials with a variety of immune interventions (45,46) that will not be discussed here. Rather, this discussion is confined to randomized controlled trials and studies that have either tested contemporary immunologic approaches or ones that offer special insights.

### Early Intervention Studies

#### Cyclosporine

A pilot study by Stiller et al. (47), reported in 1984, used cyclosporine, an immunosuppressive agent targeting T lymphocytes, which served to stimulate the field, including the conduct of a number of cyclosporine studies (75,76,77,78,79,80). Two large randomized controlled trials compared “remission” rates with cyclosporine versus placebo in subjects with new-onset Stage 3 type 1 diabetes (75,76). In the French study (75), “complete remission” was defined as good metabolic control (aiming at fasting blood glucose <140 mg/dL [<7.77 mmol/L], postprandial blood glucose <200 mg/dL [<11.10 mmol/L], and glycosylated hemoglobin [A1c] <7.5% [<58 mmol/mol]) in the absence of insulin treatment. “Partial remission” was defined by the same metabolic criteria obtained with <0.25 units/kg per day of insulin. In the Canadian-European study (76), the same metabolic targets were used, but “remission” also required a stimulated C-peptide level >0.6 nmol/L or a non-insulin requiring (NIR) state. Doses of cyclosporine were progressively lowered and stopped after a period of time if remission was not achieved.

Both studies showed a greater proportion of subjects in remission with cyclosporine than with placebo, but the rate of remission progressively declined in both groups during the 1-year course of the study. Two smaller studies, in Miami (77) and Denver (78), also were conducted. The Miami study showed a slower rate of decline of stimulated C-peptide with cyclosporine compared to placebo. The Denver study showed a slightly greater, but not statistically significant, difference in the rate of remission in the cyclosporine group than the placebo group. Meanwhile, buoyed by two randomized controlled trials showing the beneficial effects of cyclosporine, a French team initiated a study of cyclosporine in which all eligible subjects received the drug (79). In that study, 27 of 40 subjects (67.5%), all of whom were children, achieved remission. Enrollment was expanded, and subjects were followed for a protracted period of time, during which subjects lost their remission in spite of continued cyclosporine therapy (80). This lack of long-term benefit, coupled with the then-emerging recognition of cyclosporine side effects (particularly renal disease), led to virtual abandonment of this therapy in type 1 diabetes.

#### Azathioprine

In the same era, the mid-1980s, several studies were conducted with azathioprine, an immunomodulatory agent, in recent-onset Stage 3 type 1 diabetes (81,82,83). One study initiated therapy with a 10-week course of corticosteroids followed by 1 year of treatment with azathioprine and found better beta cell function at 1 year, as measured by peak C-peptide/glucose ratio, than in the randomized but untreated control group (81). Another, nonrandomized study gave alternate patients azathioprine and found that most azathioprine subjects achieved “remission,” whereas only one comparison subject did (82). A third azathioprine study was a double-masked placebo-controlled study that enrolled 49 people age 2–20 years with newly diagnosed type 1 diabetes (83). This study found nearly equal rates of remission in both groups. Given the nonrandomized nature of the other studies and the side effects of azathioprine, further studies with azathioprine were not pursued.

#### Linomide

The immunomodulatory agent linomide (quinoline-3-carboxamide), thought to activate or modulate regulatory T lymphocytes, was evaluated in a randomized placebo-controlled trial in 63 subjects age 10–20 years with recent-onset Stage 3 type 1 diabetes (84). Subjects were treated for 1 year, and beta cell function was evaluated by glucagon-stimulated C-peptide. Although the initial analysis suggested no difference between groups, when the analysis was confined to those with residual C-peptide at baseline (40 of 63 subjects), a beneficial effect was observed. Although side effects were minimal, the manufacturer did not continue development of linomide, and thus, this was not further pursued.

#### Bacille Calmette-Guerin Vaccine

Two double-masked placebo-controlled trials in the 1990s evaluated the effects of BCG (bacille Calmette-Guerin) vaccine, an immune regulatory agent that showed benefit in animal models, in subjects with recent-onset Stage 3 type 1 diabetes (85,86). One, conducted in Alberta, Canada (85), enrolled 26 subjects with mean age 13 years, while the other, conducted in Colorado and Massachusetts (86), enrolled 94 subjects age 5–18 years. Similar outcomes were seen in both studies, namely that there was no effect of BCG on preservation of beta cell function. Indeed, in both studies, there was a trend to greater decline of beta cell function in the BCG group than in the control group.

TABLE 37.2 Intervention Studies in Recent-Onset Type 1 Diabetes

STUDY NAME (REF.) | INTERVENTION | NUMBER RANDOMIZED | ACTIVE: PLACEBO | AGE RANGE (YEARS) | PRIMARY OUTCOME | TIME OF PRIMARY OUTCOME | OUTCOME | P-VALUE
Early intervention studies (1970–2000)
French Cyclosporine (75) | Cyclosporine | 122 | 1:1 | 15–40 | Remission | 9 months | 24.1% vs. 5.8% | <0.01
Canadian-European Cyclosporine (76) | Cyclosporine | 188 | 1:1 | 9–35 | C-peptide ≥0.6 nmol/L or non-insulin requiring | 1 year | 33.0% vs. 20.7% | 0.004
Miami Cyclosporine Trial (77) | Cyclosporine | 23 | 1:1 | 9–38 | MMTT C-peptide | 1 year | Slower rate of decline | <0.05
Denver Cyclosporine Trial (78) | Cyclosporine | 43 | 1:1 | 8–36 | Remission | 1 year | 27.2% vs. 19.0% | NS
French Pediatric Cyclosporine (79,80) | Cyclosporine | 40 | All treated (no controls) | 7–15 | Remission | 1 year | 67.5% | NA
Azathioprine + Glucocorticoids (81) | Azathioprine and Prednisone | 46 | 1:1 | 4–33 | Peak C-peptide/glucose ratio | 1 year | 44.1 vs. 14.2 | <0.01
Azathioprine – Adults (82) | Azathioprine | 24 | 1:1 | 15–50 | Remission | 1 year | 53.8% vs. 9.1% | <0.05
Azathioprine – Children (83) | Azathioprine | 49 | 1:1 | 2–20 | Partial remission | 1 year | 17% vs. 16% | NS
Linomide French Trial (84) | Linomide | 63 | 2:1 | 10–20 | Glucagon-stimulated C-peptide | 1 year | 0.38 vs. 0.25 nmol/L | <0.05
BCG (85) | BCG vaccine | 26 | 1:1 | Mean 13 | Glucagon-stimulated C-peptide | 18 months | 0.20 vs. 0.30 nmol/L | NS
BCG (86) | BCG vaccine | 94 | 1:1 | 5–18 | 1°: Remission; 2°: MMTT; C-peptide | 2 years | 1°: 2.5% vs. 2.6%; 2°:No diff | NS
French Oral Insulin (87) | Oral insulin (two doses: 2.5 mg, 7.5 mg) | 131 | 1:1:1 | 7–40 | Glucagon-stimulated C-peptide | 1 year | 0.39 vs. 0.37 vs. 0.33 nmol/L | NS
Italian Oral Insulin (88) | Oral insulin (5 mg) | 82 | 1:1 | 5–36 | Fasting C-peptide | 1 year | 0.17 vs. 0.22 nmol/L | NS
U.S. Oral Insulin (89) | Oral insulin (two doses: 1 mg, 10 mg) | 191 | 1:1:1 | 5–80 | Loss of C-peptide | 6–36 months | * | *
Anti-CD5 Pilot (90) | Anti-CD5 immunotoxin | 15 | All treated (no controls) | 17–40 | MMTT C-peptide | 1 year | Slope not different from zero | NA
Anti-CD3 intervention studies
Herold Anti-CD3 (91,92) | Teplizumab | 24 | 1:1 | 7–30 | MMTT C-peptide | 1 year | 114.2 vs. 66.7 nmol/L | <0.01
Keymeulen Anti-CD3 (93,94) | Otelixizumab | 80 | 1:1 | 12–39 | C-peptide after clamp | 1 year | 0.8 vs. 0.6 nmol/L/min | <0.01
Protégé (95,96) | Teplizumab (three treatment regimens) | 516 | 2:1:1:1 | 8–35 | Insulin <0.5 u/kg and A1c <6.5% | 1 year | 19.8%, 13.7%, 20.8%, 20.4% | NS
Protégé Encore (97) | Teplizumab | 256 | NA | 8–35 | Insulin <0.5 u/kg and A1c <6.5% | 1 year | NA | NA
DEFEND-1 (98) | Otelixizumab | 281 | 2:1 | 12–45 | MMTT C-peptide | 1 year | −0.20 vs.−0.22 nmol/L | NS
DEFEND-2 (99) | Otelixizumab | 179 | 2:1 | 12–45 | MMTT C-peptide | 1 year | −0.23 vs. −0.13 nmol/L | NS
AbATE (ITN study) (100) | Teplizumab | 83 | 2:1 | 8–29 | MMTT C-peptide | 2 years | −0.28 vs. −0.46 nmol/L | 0.002
Delay (101) | Teplizumab | 63 | 1:1 | 8–28 | MMTT C-peptide | 1 year | 0.45 vs. 0.37 nmol/L | 0.03
GAD intervention studies
GAD Pilot (102) | GAD-Alum vaccine | 70 | 1:1 | 10–18 | Fasting C-peptide | 15 months | −0.12 vs. −0.17 nmol/L | NS
GAD TrialNet (103) | GAD-Alum vaccine (two dose regimens) | 145 | 1:1:1 | 3–45 | MMTT C-peptide | 1 year | 0.41 vs. 0.38 vs. 0.41 nmol/L | NS
GAD Europe (104) | GAD-Alum vaccine (two dose regimens) | 334 | 1:1:1 | 10–20 | MMTT C-peptide | 1 year | All approx. −0.33 nmol/L | NS
GAD U.S. (DIAPREVENT) (105) | GAD-Alum vaccine (two dose regimens) | 328 | 1:1:1 | 10–20 | MMTT C-peptide | 1 year | NA | NS
DiaPep277 intervention studies
DiaPep – Israeli adults (106,107) | DiaPep277 peptide | 35 | 1:1 | 16–55 | Glucagon-stimulated C-peptide | 10 months | 0.93 vs. 0.26 nmol/L | 0.039
DiaPep – Israeli children (108) | DiaPep277 peptide | 30 | 1:1 | 7–14 | MMTT C-peptide | 1 year | 0.21 vs. 0.17 nmol/L | NS
DiaPep – Belgian adults (109) | DiaPep277 peptide (three doses: 0.2 mg, 1.0 mg, 2.5 mg) | 48 | 1:1:1:1 | 18–45 | Glucagon-stimulated C-peptide | 1 year | −2.5, −2.5, −0.5, −5.0 nmol/min/L | 0.03^†^ 2.5 mg dose
DiaPep – Europe adults (110) | DiaPep277 peptide (three doses: 0.2 mg, 1.0 mg, 2.5 mg) | 50 | 1:1:1:1 | 16–44 | Glucagon-stimulated C-peptide | 18 months | Similar change | NS
DiaPep – Europe children (110) | DiaPep277 peptide (two doses: 0.2 mg, 1.0 mg) | 49 | 1:1:1 | 4–15 | Glucagon-stimulated C-peptide | 18 months | Similar change | NS
DiaPep – Phase III (111,112) | DiaPep277 peptide | 457 | 1:1 | 16–45 | Glucagon-stimulated C-peptide | 24 months | ^‡^ | ^‡^
Other TrialNet intervention studies
MMF-DZB (115) | Mycophenolate mofetil (MMF) and daclizumab (DZB) | 126 | 1:1:1 | 8–45 | MMTT C-peptide | 2 years | 0.25 vs. 0.28 vs. 0.27 nmol/L | NS
Anti-CD20 (116,117) | Anti-CD20 Rituximab | 87 | 2:1 | 8–40 | MMTT C-peptide | 1 year | 0.56 vs. 0.47 nmol/L | 0.03
Abatacept (118,119) | Abatacept | 112 | 2:1 | 6–45 | MMTT C-peptide | 2 years | 0.378 vs. 0.238 nmol/L | 0.0029
Canakinumab (120) | Anti-IL1β canakinumab | 71 | 2:1 | 6–45 | MMTT C-peptide | 1 year | Diff =0.01 nmol/L | NS
Other ITN intervention studies
START Thymoglobulin (121) | Thymoglobulin | 58 | 2:1 | 12–35 | MMTT C-peptide | 1 year | −0.195 vs. −0.239 nmol/L | NS
T1DAL – Alefacept (122) | Alefacept | 49 | 2:1 | 12–35 | MMTT; C-peptide:; 1°: 2 hours; 2°: 4 hours | 1 year | 1°: +0.015 vs. −0.115 nmol/L; 2°: +0.015 vs. −0.156 nmol/L | 0.065; 0.019
Insulin B-Chain (124) | Insulin B-chain | 12 | 1:1 | 18–35 | MMTT C-peptide | 1 year | Similar change | NS
IL-2 & Rapamycin Safety (125) | IL-2 and rapamycin | 9 | All treated (no controls) | 20–36 | MMTT C-peptide | 1 year | 43% decrease at 3 months | NA
Other recent intervention studies
AIDA Anakinra Trial (120) | Anakinra | 69 | 1:1 | 18–35 | MMTT C-peptide | 9 months | Diff =0.02 nmol/L | NS
Alpha-1 Antitrypsin (AAT) (126) | AAT | 12 | All treated (no controls) | 12–39 | MMTT C-peptide | 1 year | * | NA
Altered peptide ligand (APL) (127) | B9–23 APL (three doses) | 188 | 1:1:1:1 | 10–35 | MMTT C-peptide | 24 months | 0.59, 0.57, 0.48, 0.54 nmol/L | NS
Plasmid-encoded proinsulin (128) | Plasmid-encoded proinsulin (four doses) | 80 | 1:1:1:1:2 | 18–40 | Safety and MMTT C-peptide | 2 years | * | NS
Proinsulin peptide (129) | Proinsulin peptide (two doses) | 48 | 1.5:1.5:1 | 21–53 | Safety study | 6 months | No safety issues | ^§^
ATG – GCSF Trial (130) | Thymoglobulin and granulocyte colony-stimulating factor (GCSF) | 25 | 2:1 | 12–45 | MMTT C-peptide | 1 year | 0.74 vs. 0.43 nmol/L/min | 0.05
DIATOR (133,134) | Atorvastatin | 89 | 1:1 | 18–39 | MMTT C-peptide | 18 months | 0.78 vs. 0.41 nmol/L | NS
Etanercept (135) | Etanercept | 18 | 1:1 | 7–18 | MMTT C-peptide | 6 months | +39% vs. -20% | 0.05
Low-Dose IL-2 Safety Trial (136) | IL-2 (three doses) | 24 | 1:1:1:1 | 18–55 | Treg number | 60 days | Increased Tregs | NA
REPAIR-T1D (137) | Sitagliptin and lansoprazole | 68 | 2:1 | 11–36 | MMTT C-peptide | 1 year | -229 vs. -253 pmol/L | NS
AHSCT + Profound Immunosuppression (138,139,140) | Cyclophosphamide, GCSF, ATG, AHSCT | 23 | All treated (no controls) | 13–31 | MMTT C-peptide | 2 years | Increase from 225 to 785 ng/ml/2-hour | 0.001
AHSCT + Profound Immunosuppression (141) | Cyclophosphamide, GCSF, ATG, AHSCT | 65 | All treated (no controls) | 12–35 | MMTT C-peptide | 6 months | Increase from 0.54 to 1.22 ng/ml | 0.0001
Ongoing intervention studies^ǁ^
ATG – GCSF Trial (132) | Thymoglobulin and GCSF | Enrolling Target: 84 | 1:1:1 | 12–45 | MMTT C-peptide | 1 year | ^¶^ | ^¶^
EXTEND Trial (142) | Tocilizumab | Enrolling Target: 108 | 2:1 | 6–45 | MMTT C-peptide | 1 year | ^¶^ | ^¶^
Otelixizumab Dose Ranging Trial (143) | Otelixizumab (four doses) | Enrolling Target: 40 | 1:1:1:1:1 | 16–27 | Safety and MMTT C-peptide | 2 years | ^¶^ | ^¶^
Alpha-1 Antitrypsin (AAT) Trial (144) | AAT (two doses) | Enrolling Target: 192 | 1:1:1 | 8–25 | Basal C-peptide | 1 year | ^¶^ | ^¶^
Alpha-1 Antitrypsin (AAT) Trial (145) | AAT (four regimens) | Enrolling Target: 75 | 1:1:1:1:1 | 12–35 | MMTT C-peptide | 1 year | ^¶^ | ^¶^
Ustekinumab Pilot (146) | Open label pilot ustekinumab (four doses) | Enrolling Target: 20 | 1:1:1:1 | 18–35 | Safety | 1 year | ^¶^ | ^¶^
Imatinib Trial (147) | Imatinib | Enrolling Target: 66 | 2:1 | 18–45 | MMTT C-peptide | 1 year | ^¶^ | ^¶^
Tauroursodeoxycholic Acid (TUDCA) Trial (148) | TUDCA | Enrolling Target: 20 | 1:1 | 18–45 | MMTT C-peptide | 18 months | ^¶^ | ^¶^
DIABGAD (149) | GAD-Alum and vitamin D with/without ibuprofen | Enrolling Target: 60 | 1:1:1:1 | 10–18 | MMTT C-peptide | 30 months | ^¶^ | ^¶^
Proinsulin Peptide (150) | Proinsulin peptide (two dose regimens) | Enrolling Target: 24 | 1:1:1 | 18–40 | Safety | 3 years | ^¶^ | ^¶^
Methyldopa (151) | Methyldopa | Enrolling Target: 50 | All treated (no controls) | 18–46 | Inhibition of DQ8 antigen presentation; MMTT C-peptide | 12 weeks | ^¶^ | ^¶^
Low-Dose IL-2 (152) | IL-2 | Enrolling Target: 24 | 1:1:1:1 | 7–12 | Treg number | 22 days | ^¶^ | ^¶^

Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; AAT, alpha-1 antitrypsin; AbATE, Autoimmunity-Blocking Antibody for Tolerance in Recently Diagnosed Type 1 Diabetes trial; AHSCT, autologous hematopoietic stem cell therapy; AIDA, Anti-Interleukin-1 in Diabetes Action; APL, altered peptide ligand; ATG, antithymocyte globulin; BCG, bacille Calmette-Guerin; DEFEND, Trial of Otelixizumab for Adults With Newly Diagnosed Type 1 Diabetes Mellitus (Autoimmune); DIABGAD, Trial to Preserve Insulin Secretion in Type 1 Diabetes Using GAD-Alum (Diamyd) in Combination With Vitamin D and Ibuprofen; DIAPREVENT, A Phase III Study to Investigate the Impact of Diamyd in Patients Newly Diagnosed With Type 1 Diabetes; DIATOR, Diabetes and Atorvastatin Trial; DZB, daclizumab; EXTEND, Tocilizumab in New Onset Type 1 Diabetes trial; GAD, glutamic acid decarboxylase; GCSF, granulocyte colony-stimulating factor; IL, interleukin; ITN, Immune Tolerance Network; MMF, mycophenolate mofetil; MMTT, mixed meal tolerance test; NA, not applicable; NS, nonsignificant; REPAIR-T1D, Combination Therapy With Sitagliptin and Lansoprazole to Restore Pancreatic Beta Cell Function in Recent-Onset Type 1 Diabetes trial; START, Study of Thymoglobulin to ARrest Type 1 diabetes; T1DAL, Inducing Remission in New Onset T1DM with Alefacept trial; TUDCA, tauroursodeoxycholic acid.

* Data are ambiguous.

† Outcome was significant in one of three dosages.

‡ The paper was retracted.

§ Randomized safety study

ǁ As of January 2017

¶ Data are not yet available as of January 2017.

SOURCE: References are listed within the table.

#### Oral Insulin

Three studies used oral insulin (in various doses) in recent-onset Stage 3 type 1 diabetes (87,88,89). In the French (87) and Italian (88) studies, no effect was seen on beta cell function. In the study conducted in the United States (89), retention of endogenous beta cell function was said to be dependent upon initial stimulated C-peptide response, age at diabetes onset, and numbers of specific islet cell autoantibodies found. The complex analysis did not permit a clear conclusion to be drawn, particularly in view of the two negative European studies.

#### Anti-CD5 Monoclonal Antibody

Using an anti-CD5 monoclonal antibody, which targets T lymphocytes, linked to ricin A-chain, a toxin, a small open-label dose-escalation pilot study was conducted in 15 subjects with recent-onset Stage 3 type 1 diabetes (90). With only 5 days of treatment, there appeared to be a slower than anticipated decline in beta cell function (tested by a mixed meal tolerance test [MMTT]) over 1 year, but in the absence of a control group, it was not possible to infer a beneficial effect. Nonetheless, the use of a monoclonal antibody directed at T lymphocytes served to stimulate other investigations of monoclonal antibodies in type 1 diabetes.

### Anti-CD3 Intervention Studies

Extensive studies have been conducted with two anti-CD3 monoclonal antibodies targeting T lymphocytes—teplizumab and otelixizumab—which are humanized Fc-mutated (Fc receptor [FcR] nonbinding) monoclonal antibodies. The first study reported was a small study involving only 12 treated subjects and 12 untreated comparison subjects (91). They received a single 14-day course of treatment with teplizumab within 6 weeks of diagnosis of Stage 3 type 1 diabetes and were found to have slower decline of beta cell function (by MMTT) at 1 year (91). In these and an expanded group of subjects (total of 21 treated, 21 untreated), there was sustained improvement of beta cell function at 2 years (92). Meanwhile, the otelixizumab study was the first randomized placebo-controlled trial with an anti-CD3 monoclonal antibody (93). In it, 80 subjects age 12–39 years, within 4 weeks from diagnosis of Stage 3 type 1 diabetes, were randomized to a 6-day course of either otelixizumab or placebo and followed for 18 months. Beta cell function measured using a hyperglycemic clamp followed by glucagon stimulation was found to be better in the otelixizumab than the placebo group, particularly in subjects with higher baseline insulin secretory response (93). After 4 years of follow-up, although beta cell function was not measured, the otelixizumab group had lower insulin requirements despite similar glycemic control as measured by A1c (94). Thus, effects of a 6-day treatment course were evident 4 years later.

The results from these early Phase 2 studies with anti-CD3 treatment led to the initiation of Phase 3 clinical trials with both agents. However, the Phase 3 studies did not meet their primary outcome criteria. For teplizumab, the primary outcome was the combination of A1c <6.5% (<48 mmol/mol) and insulin dose <0.5 units/kg/day (95,96,97). This outcome measure was arbitrarily selected and highly criticized for a number of reasons. Moreover, by using a composite outcome that requires a subject to meet two criteria, the outcome became a dichotomous measure that dilutes the effect of two continuous variables—A1c and insulin dose. More importantly, when the conventional outcome measure of C-peptide was assessed, there was evidence of efficacy both at 1 year (95) and at 2 years (96) following two 14-day courses of teplizumab (at entry and at 26 weeks into the study). This was especially evident in subjects enrolled in the United States (who had lower A1c at entry and during study), in younger subjects (age 8–17 years), in subjects enrolled within 6 weeks of diagnosis, and in subjects with higher levels of C-peptide at entry (95). For otelixizumab, the Phase 3 studies used a dose that was one-sixteenth (total of 3.1 mg over 8 days) that used in the positive Phase 2 study described in the previous paragraph (total of 48 mg), in an effort to avoid any side effects (98,99). Not only were side effects completely obviated, but beneficial effects were also obviated. This outcome highlights the challenge with significant dose reduction—all effective therapies are likely to have some side effects, and eliminating the side effects of a drug may also eliminate its potential benefits.

Two other studies with teplizumab are worth noting. In the Autoimmunity-Blocking Antibody for Tolerance in Recently Diagnosed Type 1 Diabetes (AbATE) Trial, conducted by the Immune Tolerance Network (ITN), there was demonstration of efficacy (100). More importantly, however, subjects could be divided into two groups—“responders” and “nonresponders” to treatment. Responders were those who maintained C-peptide better than the randomized, but untreated, comparison group at 24 months. This group, which constituted 45% of subjects treated with teplizumab, maintained beta cell function for 2 years, whereas the nonresponders lost beta cell function at a rate similar to the control group (100). In another teplizumab study, the Delay trial, subjects diagnosed with Stage 3 type 1 diabetes at least 4 but not more than 12 months before enrollment (thus “Delayed” compared to recent onset), were randomized to receive infusions of either teplizumab or placebo (101). There was a slowing in the decline of beta cell function in the group as a whole, driven by beneficial effect in those treated within 4–8 months of diagnosis, as the effects were not significant in the subgroup treated 9–12 months after diagnosis.

### GAD Intervention Studies

A vaccine, consisting of GAD with the adjuvant aluminum hydroxide (GAD-Alum), created much excitement on the basis of an initial report of a Phase 2 trial, in which there was claimed benefit, at least in those subjects enrolled early after diagnosis (102). However, this result was not confirmed in a TrialNet study (103) nor in two Phase 3 trials conducted by the manufacturer (104,105).

### DiaPep277 Intervention Studies

Several Phase 2 clinical trials were conducted using DiaPep277, a 24 amino acid peptide derived from heat shock protein 60 (106,107,108,109,110). The first of the Phase 2 trials appeared to have promising results (106,107), but the results from the other Phase 2 trials (108,109,110) were conflicting. A Phase 3 trial was reported and had inherently confusing results with improved C-peptide versus placebo during a glucagon-stimulated test, but no difference between groups with an MMTT (111,112). Subsequently, the papers describing this trial were retracted, because there may have been efforts to “manipulate the analyses to obtain a favorable result” (113,114).

### Other Trialnet Intervention Studies

Type 1 Diabetes TrialNet has conducted four other studies with immunologic interventions in subjects with recently diagnosed type 1 diabetes. All studies enrolled subjects within 100 days of diagnosis of recent-onset Stage 3 type 1 diabetes and measured beta cell function by C-peptide in response to serial MMTTs.

One study evaluated the immunosuppressive agent mycophenolate mofetil, either alone or in combination with the anti-CD25 monoclonal antibody daclizumab, which targets the alpha chain of the IL-2 receptor expressed on T lymphocytes (115). The study enrolled 126 subjects age 8–45 years. It was stopped early by the Data and Safety Monitoring Board due to futility of the potential of seeing a beneficial treatment effect (115).

Another TrialNet study evaluated the anti-CD20 monoclonal antibody rituximab, which depletes B lymphocytes (116). In this study, 87 subjects age 8–40 years were randomized in a 2:1 design to receive either four weekly doses of rituximab or placebo. After 1 year, there was better maintenance of beta cell function in the rituximab group than in the placebo group, although a progressive decline was observed in the rituximab group as well (116). Over 2 years, the rate of decline of C-peptide was parallel between groups, but shifted by 8.2 months in rituximab-treated subjects (117). Thus, the effect appeared to be transient, with no fundamental alteration of the disease process.

TrialNet also evaluated effects of abatacept (soluble CTLA4Ig), which binds to CD80 and CD86, the ligands for CD28, a co-stimulatory molecule on T lymphocytes (118). In this study, 112 subjects age 6–45 years were randomized in a 2:1 design to receive either monthly infusions of abatacept or placebo for 2 years. After those 2 years, there was better maintenance of beta cell function in the abatacept group than in the placebo group, although there was a progressive decline in the abatacept group as well (118). After therapy was stopped, subjects were followed for an additional year, with the abatacept group maintaining a difference from the placebo group; a progressive parallel rate of decline was observed in both groups, but shifted by 9.5 months in abatacept-treated subjects (119). Thus, the beneficial effect was sustained for at least 1 year after cessation of abatacept infusions or 3 years from the diagnosis of type 1 diabetes.

Another treatment strategy evaluated by TrialNet was antagonism of the cytokine IL-1, thought to be a key mediator of innate immunity, as it is a proinflammatory cytokine that recruits effector T lymphocytes in inflamed tissues and also has direct toxic effects on beta cells. In the TrialNet study, which used the anti-IL-1β monoclonal antibody canakinumab, 71 subjects age 6–45 years were randomized in a 2:1 design to receive either monthly subcutaneous injections of canakinumab or placebo for 1 year (120). No difference in beta cell function was observed between groups. The canakinumab study was reported together with another study examining antagonism of IL-1, using the human IL-1 receptor antagonist anakinra (120). For the anakinra trial, 69 subjects age 18–35 years were randomized to receive either daily subcutaneous injections of anakinra or placebo for 9 months. With anakinra as well, there was no difference in beta cell function between groups. Thus, by itself, antagonism of IL-1 failed to show benefit.

### Other Immune Tolerance Network Intervention Studies

The ITN conducted a study evaluating thymoglobulin in recent-onset type 1 diabetes, the Study of Thymoglobulin to ARrest Type 1 diabetes (START) (121). In this study, 58 subjects age 12–35 years with recent-onset Stage 3 type 1 diabetes were randomized in a 2:1 design to receive either thymoglobulin (antithymocyte globulin [ATG]) or placebo over a course of 4 days. There was no between-group difference in beta cell function at 1 year. However, thymoglobulin resulted in generalized depletion of T lymphocytes rather than in the hoped-for specific depletion of effector memory T lymphocytes with preservation of regulatory T cells.

In another ITN study, the Inducing Remission in New-Onset Type 1 Diabetes with Alefacept (T1DAL) trial, alefacept was used to target memory T lymphocytes (122). In this trial, 49 subjects age 12–35 years, with recent-onset Stage 3 type 1 diabetes, were randomized in a 2:1 design to receive either alefacept or placebo, given as two 12-week courses of monthly intramuscular injections, separated by a 12-week hiatus. Because the manufacturer withdrew alefacept from production during the course of the trial, there was a smaller enrollment than planned. Beta cell function appeared to be preserved in the alefacept group, i.e., it did not decline over 12 months, but the results of the primary outcome—C-peptide during the first 2 hours of the MMTT—just missed statistical significance (p=0.065). In contrast, the secondary outcome—C-peptide during the full 4 hours of the MMTT—indicated a significant difference in beta cell function (p=0.019) (122). At 24 months, both the 4-hour and the 2-hour C-peptide levels were greater in the alefacept group than the placebo group (123). Thus, had the study been fully enrolled, the primary outcome may have been met. Moreover, alefacept did appear to have a greater impact on central memory and effector memory T lymphocytes with sparing of naïve and regulatory T lymphocyte populations. Taken together, these findings suggest that targeting memory T lymphocytes may be an attractive immunomodulatory approach.

ITN also conducted two small pilot studies. One evaluated the safety of a vaccine using human insulin B-chain in incomplete Freund’s adjuvant, administered as a single intramuscular injection (124). In this pilot safety study, 12 subjects age 18–35 years were randomized to receive either the vaccine or placebo. There were no safety issues. No difference in beta cell function was found, but there was suggestive evidence of generation of antigen-specific regulatory T lymphocytes.

The other ITN pilot study was an open label Phase 1 study using the combination of IL-2 and rapamycin (125). Nine subjects were enrolled, age 20–36 years, between 4 and 48 months from diagnosis of type 1 diabetes if they had a peak C-peptide of at least 0.4 nmol/L during an MMTT. The study was halted due to the reported acute decline in C-peptide during the first 3 months; although, without a comparison group and without much literature data on the rate of C-peptide decline in this time frame after diagnosis, it is not clear whether this was unusual. There appeared to be a subsequent recovery of C-peptide in four of the subjects. Although there was an increase in regulatory T lymphocytes, natural killer cells and eosinophils also increased, with no difference in effector T lymphocytes.

### Other Recent Intervention Studies

A pilot Phase 1 safety study used alpha-1 antitrypsin (AAT), an anti-inflammatory agent that had beneficial effects in animal models (126). No safety issues were identified. The study showed that AAT was associated with a down-modulation of IL-1β, which may indicate potential benefit for type 1 diabetes.

A study using an insulin B-chain altered peptide ligand enrolled 188 subjects age 10–35 years (127). Subjects were randomized to one of four groups—three doses of the drug or placebo. After 2 years, there was no difference in beta cell function among the four groups.

Another study evaluated a plasmid- encoded proinsulin (128). Subjects age 18–40 years were randomized to one of five groups—four doses of the drug or placebo. Although beta cell function improved at one time point for one of the four doses, the overall intervention failed to show benefit.

A pilot safety study with a proinsulin peptide enrolled 48 subjects randomized to one of two dose groups or placebo (129). The study showed no safety issues and serves as a basis for additional studies.

Another small pilot study has been done with the combination of low-dose ATG and pegylated granulocyte colony-stimulating factor (GCSF) (130). This study enrolled 25 subjects age 12–45 years with type 1 diabetes of 4–24 months duration, randomized 2:1 to active treatment or placebo. Subjects received intravenous ATG (or placebo) over 2 days, followed by subcutaneous GCSF every 2 weeks for six doses. At the end of 1 year, beta cell function was preserved, as measured by MMTT. At the end of 2 years, the difference between groups was no longer statistically significant (131). A larger study in recent-onset Stage 3 type 1 diabetes is being conducted to pursue these observations (132).

The Diabetes and Atorvastatin (DIATOR) Trial randomized 89 subjects age 18–39 years to atorvastatin or placebo, on the basis that atorvastatin appears to have immunomodulatory properties (133). This provocative study did not meet its primary outcome (difference in C-peptide between groups at 18 months). However, when the authors examined the decline in C-peptide within the atorvastatin group, there was a nonsignificant decline, whereas the decline in C-peptide within the placebo group was significant (133). A further analysis suggested that individuals with markers of inflammation may be the ones that benefit (134). Because atorvastatin is a common, orally administered generic drug, further evaluation of atorvastatin may be warranted.

A small pilot study evaluated etanercept, a blocker of the proinflammatory cytokine TNF (135). Although only 18 subjects were enrolled, the etanercept group had increased beta cell function at 6 months, whereas the placebo group had decreased beta cell function at that time, thus achieving statistical significance between groups.

A small safety study, involving 24 subjects, evaluated three dosing regimens of a relatively low dose of IL-2 (136). There was an increase in regulatory T lymphocytes, and no safety issues emerged, including no decline in C-peptide that was reported with higher doses of IL-2 in combination with rapamycin (125).

One study examined the effects of the combination of sitagliptin and lansoprazole in patients with recent-onset Stage 3 type 1 diabetes (137). The rationale of this study was that a dipeptidyl-peptidase 4 (DPP-4) inhibitor (sitagliptin) would increase serum levels of glucagon-like peptide-1 (GLP-1), while a proton pump inhibitor (lansoprazole) would increase serum levels of gastrin. In experimental animals, the combination GLP-1 and gastrin has been shown to increase beta cell mass and function. The human study—REPAIR T1D—randomized 68 subjects age 11–36 years in a 2:1 design to receive either the combination of sitagliptin and lansoprazole or placebo for both drugs. At 1 year, there was no difference in the rate of decline of beta cell function comparing treated subjects and control subjects (137).

In 2007, a group of investigators from Brazil reported an open label trial of 15 patients with Stage 3 type 1 diabetes age 13–31 years diagnosed within the previous 6 weeks, who were treated with the combination of high-dose immunotherapy, with cyclophosphamide and ATG, together with nonmyeloablative autologous hematopoietic stem cell therapy (AHSCT) using CD34+ cells isolated from bone marrow (138). They reported that during 7–36 months of follow-up, 14 of 15 subjects became insulin free. Subsequently, they updated their findings in a total of 23 subjects, asserting that 20 had achieved freedom from insulin therapy, with 12 of them maintaining that for a mean of 31 months (139,140). Additional studies from Poland and China were subsequently conducted, and the Polish and Chinese data have been summarized (141). Their findings confirmed that a substantial number of subjects achieved insulin independence. However, substantial side effects occurred, including a death from Pseudomonas sepsis (141), and the death rate in other disease states with AHSCT can be as high as 25%. In addition, these were all nonrandomized open label studies, with incomplete characterization of the subjects, so it is not clear that all had autoimmune type 1 diabetes.

### Ongoing Intervention Studies

Thus, several provocative studies demonstrating at least transient preservation of beta cell function have been conducted, but no controlled studies have demonstrated sufficient sustained beta cell function, such that insulin therapy is not required. Additional studies are underway with a variety of approaches (132,142,143,144,145,146,147,148,149,150,151,152). It may be that a combination approach is needed, perhaps one that combines an anti-inflammatory agent targeting innate immunity, with an immunomodulatory agent targeting adaptive immunity, with agents that stimulate regulatory immunity, and an agent that helps preserve beta cell health (153).

## List of Abbreviations

A1c: glycosylated hemoglobin
AAT: alpha-1 antitrypsin
AHSCT: autologous hematopoietic stem cell therapy
ATG: antithymocyte globulin
BCG: bacille Calmette-Guerin
CI: confidence interval
DENIS: German (Deutsch) Nicotinamide Diabetes Intervention Study
DHA: docosahexaenoic acid
DIPP: Diabetes Prediction and Prevention Study
DPT-1: Diabetes Prevention Trial-Type 1
ENDIT: European Nicotinamide Diabetes Intervention Trial
FINDIA: Finnish Dietary Intervention Trial for the Prevention of Type 1 Diabetes
GAD: glutamic acid decarboxylase
GCSF: granulocyte colony-stimulating factor
GLP: glucagon-like peptide
HLA: human leukocyte antigen
HR: hazard ratio
IA2: islet antibody-2
IAA: insulin autoantibodies
ICA: islet cell antibodies
IL: interleukin
INIT: Intranasal Insulin Trial
ITN: Immune Tolerance Network
MMTT: mixed meal tolerance test
NIP: Nutritional Intervention to Prevent Type 1 Diabetes
OR: odds ratio
Pre-POINT: Primary Oral Insulin Therapy Study
TNF: tumor necrosis factor
TRIGR: Trial to Reduce the Incidence of Diabetes in the Genetically at Risk

## References

1 Eisenbarth GS: Type I diabetes mellitus. A chronic autoimmune disease. N Engl J Med 314:1360–1368, 1986 3517648
2 Bluestone JA, Herold K, Eisenbarth G: Genetics, pathogenesis and clinical interventions in type 1 diabetes. Nature 464:1293–1300, 2010 20432533
3 Atkinson MA, Eisenbarth GS, Michels AW: Type 1 diabetes. Lancet 383:69–82, 2014 23890997
4 Atkinson MA, Bluestone JA, Eisenbarth GS, Hebrok M, Herold KC, Accili D, Pietropaolo M, Arvan PR, Von Herrath M, Markel DS, Rhodes CJ: How does type 1 diabetes develop? The notion of homicide or β-cell suicide revisited. Diabetes 60:1370–1379, 2011 21525508
5 Nerup J, Platz P, Andersen OO, Christy M, Lyngsoe J, Poulsen JE, Ryder LP, Nielsen LS, Thomsen M, Svejgaard A: HL-A antigens and diabetes mellitus. Lancet 2:864–866, 1974 4137711
6 Schenker M, Hummel M, Ferber K, Walter M, Keller E, Albert ED, Janka HU, Kastendiek C, Sorger M, Louwen F, Ziegler AG: Early expression and high prevalence of islet autoantibodies for DR3/4 heterozygous and DR4/4 homozygous offspring of parents with type I diabetes: the German BABYDIAB study. Diabetologia 42:671–677, 1999 10382586
7 Redondo MJ, Fain PR, Eisenbarth GS: Genetics of type 1A diabetes. Recent Prog Horm Res 56:69–89, 2001 11237226
8 Lambert AP, Gillespie KM, Thomson G, Cordell HJ, Todd JA, Gale EA, Bingley PJ: Absolute risk of childhood-onset type 1 diabetes defined by human leukocyte antigen class II genotype: a population-based study in the United Kingdom. J Clin Endocrinol Metab 89:4037–4043, 2004 15292346
9 Thomson G, Valdes AM, Noble JA, Kockum I, Grote MN, Najman J, Erlich HA, Cucca F, Pugliese A, Steenkiste A, Dorman JS, Caillat-Zucman S, Hermann R, Ilonen J, Lambert AP, Bingley PJ, Gillespie KM, Lernmark A, Sanjeevi CB, Ronningen KS, Undlien DE, Thorsby E, Petrone A, Buzzetti R, Koeleman BP, Roep BO, Saruhan-Direskeneli G, Uyar FA, Gunoz H, Gorodezky C, Alaez C, Boehm BO, Mlynarski W, Ikegami H, Berrino M, Fasano ME, Dametto E, Israel S, Brautbar C, Santiago-Cortes A, Frazer de Llado T, She JX, Bugawan TL, Rotter JI, Raffel L, Zeidler A, Leyva-Cobian F, Hawkins BR, Chan SH, Castano L, Pociot F, Nerup J: Relative predispositional effects of HLA class II DRB1-DQB1 haplotypes and genotypes on type 1 diabetes: a meta-analysis. Tissue Antigens 70:110–127, 2007 17610416
10 Erlich H, Valdes AM, Noble J, Carlson JA, Varney M, Concannon P, Mychaleckyj JC, Todd JA, Bonella P, Fear AL, Lavant E, Louey A, Moonsamy P; Type 1 Diabetes Genetics Consortium: HLA DR-DQ haplotypes and genotypes and type 1 diabetes risk: analysis of the Type 1 Diabetes Genetics Consortium families. Diabetes 57:1084–1092, 2008 18252895
11 Noble JA, Valdes AM, Varney MD, Carlson JA, Moonsamy P, Fear AL, Lane JA, Lavant E, Rappner R, Louey A, Concannon P, Mychaleckyj JC, Erlich HA; Type 1 Diabetes Genetics Consortium: HLA class I and genetic susceptibility to type 1 diabetes: results from the Type 1 Diabetes Genetics Consortium. Diabetes 59:2972–2979, 2010 20798335
12 Pugliese A, Gianani R, Moromisato R, Awdeh ZL, Alper CA, Erlich HA, Jackson RA, Eisenbarth GS: HLA-DQB1*0602 is associated with dominant protection from diabetes even among islet cell antibody-positive first-degree relatives of patients with IDDM. Diabetes 44:608–613, 1995 7789622
13 Concannon P, Rich SS, Nepom GT: Genetics of type 1A diabetes. N Engl J Med 360:1646–1654, 2009 19369670
14 Barrett JC, Clayton DG, Concannon P, Akolkar B, Cooper JD, Erlich HA, Julier C, Morahan G, Nerup J, Nierras C, Plagnol V, Pociot F, Schuilenburg H, Smyth DJ, Stevens H, Todd JA, Walker NM, Rich SS; Type 1 Diabetes Genetics Consortium: Genome-wide association study and meta-analysis find that over 40 loci affect risk of type 1 diabetes. Nat Genet 41:703–707, 2009 19430480
15 Noble JA, Erlich HA: Genetics of type 1 diabetes. Cold Spring Harb Perspect Med 2:a007732, 2012 22315720
16 Steck AK, Rewers MJ: Genetics of type 1 diabetes. Clin Chem 57:176–185, 2011 21205883
17 Knip M, Simell O: Environmental triggers of type 1 diabetes. Cold Spring Harb Perspect Med 2:a007690, 2012 22762021
18 Eringsmark Regnell SE, Lernmark A: The environment and the origins of islet autoimmunity and type 1 diabetes. Diabet Med 30:155–160, 2013 23252770
19 TEDDY Study Group: The Environmental Determinants of Diabetes in the Young (TEDDY) study: study design. Pediatr Diabetes 8:286–298, 2007 17850472
20 Hagopian WA, Erlich H, Lernmark A, Rewers M, Ziegler AG, Simell O, Akolkar B, Vogt R, Jr., Blair A, Ilonen J, Krischer J, She J; TEDDY Study Group: The Environmental Determinants of Diabetes in the Young (TEDDY): genetic criteria and international diabetes risk screening of 421 000 infants. Pediatr Diabetes 12:733–743, 2011 21564455
21 Peakman M: Immunological pathways to β-cell damage in type 1 diabetes. Diabet Med 30:147–154, 2013 23199020
22 Roep BO, Tree TI: Immune modulation in humans: implications for type 1 diabetes mellitus. Nat Rev Endocrinol 10:229–242, 2014 24468651
23 Gepts W: Pathologic anatomy of the pancreas in juvenile diabetes mellitus. Diabetes 14:619–633, 1965 5318831
24 Arif S, Tree TI, Astill TP, Tremble JM, Bishop AJ, Dayan CM, Roep BO, Peakman M: Autoreactive T cell responses show proinflammatory polarization in diabetes but a regulatory phenotype in health. J Clin Invest 113:451–463, 2004 14755342
25 Coppieters KT, Dotta F, Amirian N, Campbell PD, Kay TW, Atkinson MA, Roep BO, von Herrath MG: Demonstration of islet-autoreactive CD8 T cells in insulitic lesions from recent onset and long-term type 1 diabetes patients. J Exp Med 209:51–60, 2012 22213807
26 Bottazzo GF, Florin-Christensen A, Doniach D: Islet-cell antibodies in diabetes mellitus with autoimmune polyendocrine deficiencies. Lancet 2:1279–1283, 1974 4139522
27 Ziegler AG, Nepom GT: Prediction and pathogenesis in type 1 diabetes. Immunity 32:468–478, 2010 20412757
28 Barker JM, Barriga KJ, Yu L, Miao D, Erlich HA, Norris JM, Eisenbarth GS, Rewers M; Diabetes Autoimmunity Study in the Young: Prediction of autoantibody positivity and progression to type 1 diabetes: Diabetes Autoimmunity Study in the Young (DAISY). J Clin Endocrinol Metab 89:3896–3902, 2004 15292324
29 Hummel S, Ziegler AG: Early determinants of type 1 diabetes: experience from the BABYDIAB and BABYDIET studies. Am J Clin Nutr 94(6 Suppl):1821S–1823S, 2011 21633073
30 Kupila A, Muona P, Simell T, Arvilommi P, Savolainen H, Hamalainen AM, Korhonen S, Kimpimaki T, Sjoroos M, Ilonen J, Knip M, Simell O; Juvenile Diabetes Research Foundation Centre for the Prevention of Type I Diabetes in Finland: Feasibility of genetic and immunological prediction of type 1 diabetes in a population-based cohort. Diabetologia 44:290–297, 2001 11317658
31 Ziegler AG, Rewers M, Simell O, Simell T, Lempainen J, Steck A, Winkler C, Ilonen J, Veijola R, Knip M, Bonifacio E, Eisenbarth GS: Seroconversion to multiple islet autoantibodies and risk of progression to diabetes in children. JAMA 309:2473–2479, 2013 23780460
32 Insel RA, Dunne JL, Atkinson MA, Chiang JL, Dabelea D, Gottlieb PA, Greenbaum CJ, Herold KC, Krischer JP, Lernmark A, Ratner RE, Rewers MJ, Schatz DA, Skyler JS, Sosenko JM, Ziegler AG: Staging presymptomatic type 1 diabetes: a scientific statement of JDRF, the Endocrine Society, and the American Diabetes Association. Diabetes Care 38:1964–1974, 2015 26404926
33 Sosenko JM, Skyler JS, Herold KC, Palmer JP; Type 1 Diabetes TrialNet and Diabetes Prevention Trial-Type 1 Study Groups: The metabolic progression to type 1 diabetes as indicated by serial oral glucose tolerance testing in the Diabetes Prevention Trial-Type 1. Diabetes 61:1331–1337, 2012 22618768
34 Ferrannini E, Mari A, Nofrate V, Sosenko JM, Skyler JS; DPT-1 Study Group: Progression to diabetes in relatives of type 1 diabetic patients: mechanisms and mode of onset. Diabetes 59:679–685, 2010 20028949
35 Ferrannini E, Mari A: β-cell function in type 2 diabetes. Metabolism 63:1217–1227, 2014 25070616
36 Sosenko JM, Skyler JS, Beam CA, Krischer JP, Greenbaum CJ, Mahon J, Rafkin LE, Matheson D, Herold KC, Palmer JP; Type 1 Diabetes TrialNet and Diabetes Prevention Trial-Type 1 Study Groups: Acceleration of the loss of the first-phase insulin response during the progression to type 1 diabetes in Diabetes Prevention Trial-Type 1 participants. Diabetes 62:4179–4183, 2013 23863814
37 Sosenko JM, Palmer JP, Rafkin-Mervis L, Krischer JP, Cuthbertson D, Mahon J, Greenbaum CJ, Cowie CC, Skyler JS; Diabetes Prevention Trial-Type 1 Study Group: Incident dysglycemia and progression to type 1 diabetes among participants in the Diabetes Prevention Trial-Type 1. Diabetes Care 32:1603–1607, 2009 19487644
38 Sosenko JM, Krischer JP, Palmer JP, Mahon J, Cowie C, Greenbaum CJ, Cuthbertson D, Lachin JM, Skyler JS; Diabetes Prevention Trial-Type 1 Study Group: A risk score for type 1 diabetes derived from autoantibody-positive participants in the Diabetes Prevention Trial-Type 1. Diabetes Care 31:528–533, 2008 18000175
39 Sosenko JM, Skyler JS, Mahon J, Krischer JP, Beam CA, Boulware DC, Greenbaum CJ, Rafkin LE, Cowie C, Cuthbertson D, Palmer JP; Type 1 Diabetes TrialNet and Diabetes Prevention Trial-Type 1 Study Groups: Validation of the Diabetes Prevention Trial-Type 1 Risk Score in the TrialNet Natural History Study. Diabetes Care 34:1785–1787, 2011 21680724
40 Greenbaum CJ, Beam CA, Boulware D, Gitelman SE, Gottlieb PA, Herold KC, Lachin JM, McGee P, Palmer JP, Pescovitz MD, Krause-Steinrauf H, Skyler JS, Sosenko JM; Type 1 Diabetes TrialNet Study Group: Fall in C-peptide during first 2 years from diagnosis: evidence of at least two distinct phases from composite Type 1 Diabetes TrialNet data. Diabetes 61:2066–2073, 2012 22688329
41 Mordes JP, Desemone J, Rossini AA: The BB rat. Diabetes Metab Rev 3:725–750, 1987 3301238
42 Anderson MS, Bluestone JA: The NOD mouse: a model of immune dysregulation. Annu Rev Immunol 23:447–485, 2005 15771578
43 Shoda LK, Young DL, Ramanujan S, Whiting CC, Atkinson MA, Bluestone JA, Eisenbarth GS, Mathis D, Rossini AA, Campbell SE, Kahn R, Kreuwel HT: A comprehensive review of interventions in the NOD mouse and implications for translation. Immunity 23:115–126, 2005 16111631
44 Leslie RD, Pyke DA: Immunosuppression of acute insulin-dependent diabetes. In Immunology of Diabetes. Irvine WJ, Ed. Edinburgh, Teviot Scientific Publications Ltd, 1980, p. 345–347
45 Skyler JS: Immune intervention studies in insulin-dependent diabetes mellitus. Diabetes Metab Rev 3:1017–1035, 1987 3315520
46 Skyler JS, Marks JB: Immune intervention in type 1 diabetes mellitus. Diabetes Reviews 1:15–42, 1993
47 Stiller CR, Dupre J, Gent M, Jenner MR, Keown PA, Laupacis A, Martell R, Rodger NW, von Graffenried B, Wolfe BM: Effects of cyclosporine immunosuppression in insulin-dependent diabetes mellitus of recent onset. Science 223:1362–1367, 1984 6367043
48 Skyler JS, Pugliese A: Immunotherapy trials for type 1 diabetes: the contribution of George Eisenbarth. Diabetes Technol Ther 15(Suppl 2):S2-13–S2-20, 2013
49 von Herrath M, Peakman M, Roep B: Progress in immune-based therapies for type 1 diabetes. Clin Exp Immunol 172:186–202, 2013 23574316
50 Skyler JS: Primary and secondary prevention of type 1 diabetes. Diabet Med 30:161–169, 2013 23231526
51 Knip M, Virtanen SM, Seppa K, Ilonen J, Savilahti E, Vaarala O, Reunanen A, Teramo K, Hamalainen AM, Paronen J, Dosch HM, Hakulinen T, Akerblom HK; Finnish TRIGR Study Group: Dietary intervention in infancy and later signs of beta-cell autoimmunity. N Engl J Med 363:1900–1908, 2010 21067382
52 Knip M, Akerblom HK, Becker D, Dosch HM, Dupre J, Fraser W, Howard N, Ilonen J, Krischer JP, Kordonouri O, Lawson ML, Palmer JP, Savilahti E, Vaarala O, Virtanen SM; TRIGR Study Group: Hydrolyzed infant formula and early β-cell autoimmunity: a randomized clinical trial. JAMA 311:2279–2287, 2014 24915259
53 Vaarala O, Ilonen J, Ruohtula T, Pesola J, Virtanen SM, Harkonen T, Koski M, Kallioinen H, Tossavainen O, Poussa T, Jarvenpaa AL, Komulainen J, Lounamaa R, Akerblom HK, Knip M: Removal of bovine insulin from cow’s milk formula and early initiation of beta-cell autoimmunity in the FINDIA pilot study. Arch Pediatr Adolesc Med 166:608–614, 2012 22393174
54 Hummel S, Pfluger M, Hummel M, Bonifacio E, Ziegler AG: Primary dietary intervention study to reduce the risk of islet autoimmunity in children at increased risk for type 1 diabetes: the BABYDIET study. Diabetes Care 34:1301–1305, 2011 21515839
55 Chase HP, Boulware D, Rodriguez H, Donaldson D, Chritton S, Rafkin-Mervis L, Krischer J, Skyler JS, Clare-Salzler M; Type 1 Diabetes TrialNet Nutritional Intervention to Prevent (NIP) Type 1 Diabetes Study Group: Effect of docosahexaenoic acid supplementation on inflammatory cytokine levels in infants at high genetic risk for type 1 diabetes. Pediatr Diabetes 16:271–279, 2015 25039804
56 Wicklow BA, Taback SP: Feasibility of a type 1 diabetes primary prevention trial using 2000 IU vitamin D3 in infants from the general population with increased HLA-associated risk. Ann N Y Acad Sci 1079:310–312, 2006 17130571
57 Gerstein HC: Cow’s milk exposure and type I diabetes mellitus. A critical overview of the clinical literature. Diabetes Care 17:13–19, 1994 8112184
58 Ziegler AG, Schmid S, Huber D, Hummel M, Bonifacio E: Early infant feeding and risk of developing type 1 diabetes-associated autoantibodies. JAMA 290:1721–1728, 2003 14519706
59 Bonifacio E, Ziegler AG, Klingensmith G, Schober E, Bingley PJ, Rottenkolber M, Theil A, Eugster A, Puff R, Peplow C, Buettner F, Lange K, Hasford J, Achenbach P; Pre-POINT Study Group: Effects of high-dose oral insulin on immune responses in children at high risk for type 1 diabetes: the Pre-POINT randomized clinical trial. JAMA 313:1541–1549, 2015 25898052
60 Raab J, Haupt F, Scholz M, Matzke C, Warncke K, Lange K, Assfalg R, Weininger K, Wittich S, Lobner S, Beyerlein A, Nennstiel-Ratzel U, Lang M, Laub O, Dunstheimer D, Bonafacio E, Achenbach P, Winkler C, Zeigler AG, Fr1da Study Group: Capillary blood islet autoantibody screening for identifying pre-type 1 diabetes in the general population: design and initial results of the Fr1da study. BMJ Open 6:e011144, 2016
61 Lampeter EF, Klinghammer A, Scherbaum WA, Heinze E, Haastert B, Giani G, Kolb H: The Deutsche Nicotinamide Intervention Study: an attempt to prevent type 1 diabetes. DENIS Group. Diabetes 47:980–984, 1998 9604880
62 Gale EA, Bingley PJ, Emmett CL, Collier T; European Nicotinamide Diabetes Intervention Trial (ENDIT) Group: European Nicotinamide Diabetes Intervention Trial (ENDIT): a randomised controlled trial of intervention before the onset of type 1 diabetes. Lancet 363:925–931, 2004 15043959
63 Diabetes Prevention Trial-Type 1 Diabetes Study Group: Effects of insulin in relatives of patients with type 1 diabetes mellitus. N Engl J Med 346:1685–1691, 2002 12037147
64 Skyler JS, Krischer JP, Wolfsdorf J, Cowie C, Palmer JP, Greenbaum C, Cuthbertson D, Rafkin-Mervis LE, Chase HP, Leschek E: Effects of oral insulin in relatives of patients with type 1 diabetes mellitus: the Diabetes Prevention Trial-Type 1. Diabetes Care 28:1068–1076, 2005 15855569
65 Skyler JS; Type 1 Diabetes TrialNet Study Group: Update on worldwide efforts to prevent type 1 diabetes. Ann N Y Acad Sci 1150:190–196, 2008 19120293
66 Vehik K, Cuthbertson D, Ruhlig H, Schatz DA, Peakman M, Krischer JP; DPT-1 and TrialNet Study Groups: Long-term outcome of individuals treated with oral insulin: Diabetes Prevention Trial-Type 1 (DPT-1) oral insulin trial. Diabetes Care 34:1585–1590, 2011 21610124
67 Vandemeulebroucke E, Gorus F, Decochez K, Weets I, Keymeulen B, De Block C, Tits J, Pipeleers DG, Mathieu C; Belgian Diabetes Registry: Insulin treatment in IA-2A-positive relatives of type 1 diabetic patients. Diabetes Metab 35:319–327, 2009 19647467
68 Nanto-Salonen K, Kupila A, Simell S, Siljander H, Salonsaari T, Hekkala A, Korhonen S, Erkkola R, Sipila JI, Haavisto L, Siltala M, Tuominen J, Hakalax J, Hyoty H, Ilonen J, Veijola R, Simell T, Knip M, Simell O: Nasal insulin to prevent type 1 diabetes in children with HLA genotypes and autoantibodies conferring increased risk of disease: a double-blind, randomised controlled trial. Lancet 372:1746–1755, 2008 18814906
69 Harrison LC, Honeyman MC, Steele CE, Stone NL, Sarugeri E, Bonafacio E, Couper JJ, Colman PG: Pancreatic beta-cell function and immune responses to insulin after administration of intranasal insulin to humans at risk for type 1 diabetes. Diabetes Care 27:2348–2355, 2004 15451899
70 Trial of intranasal insulin in children and young adults at risk of type 1 diabetes (INITII) [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT00336674?term=NCT00336674. Accessed 3 December 2016
71 Oral insulin for prevention of diabetes in relatives at risk for type 1 diabetes mellitus [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT00419562?term=NCT00419562. Accessed 3 December 2016
72 Diabetes Prevention - Immune Tolerance (DIAPREV-IT) [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT01122446?term=NCT01122446. Accessed 3 December 2016
73 Teplizumab for prevention of type 1 diabetes in relatives “at-risk” [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT01030861?term=NCT01030861. Accessed 3 December 2016
74 CTLA-4 Ig (Abatacept) for prevention of abnormal glucose tolerance and diabetes in relatives at-risk for type 1 diabetes mellitus [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT01773707?term=NCT01773707. Accessed 3 December 2016
75 Feutren G, Assan R, Karsenty G, Du Rostu H, Sirmai J, Papoz L, Vialettes B, Vexiau P, Rodier M, Lallemand A, Bach JF; Cyclosporin/Diabetes French Study Group: Cyclosporin increases the rate and length of remissions in insulin-dependent diabetes of recent onset. Results of a multicentre double-blind trial. Lancet 2:119–124, 1986 2873396
76 Cyclosporin-induced remission of IDDM after early intervention. Association of 1 yr of cyclosporin treatment with enhanced insulin secretion. The Canadian-European Randomized Control Trial Group. Diabetes 37:1574–1582, 1988 2903105
77 Skyler JS, Rabinovitch A: Cyclosporine in recent onset type I diabetes mellitus. Effects on islet beta cell function. Miami Cyclosporine Diabetes Study Group. J Diabetes Complications 6:77–88, 1992 1611143
78 Chase HP, Butler-Simon N, Garg SK, Hayward A, Klingensmith GJ, Hamman RF, O’Brien D: Cyclosporine A for the treatment of new-onset insulin-dependent diabetes mellitus. Pediatrics 85:241–245, 1990 2304776
79 Bougneres PF, Carel JC, Castano L, Boitard C, Gardin JP, Landais P, Hors J, Mihatsch MJ, Paillard M, Chaussain JL, Bach JF: Factors associated with early remission of type I diabetes in children treated with cyclosporine. N Engl J Med 318:663–670, 1988 3125434
80 Bougneres PF, Landais P, Boisson C, Carel JC, Frament N, Boitard C, Chaussain JL, Bach JF: Limited duration of remission of insulin dependency in children with recent overt type I diabetes treated with low-dose cyclosporin. Diabetes 39:1264–1272, 1990 2210078
81 Silverstein J, Maclaren N, Riley W, Spillar R, Radjenovic D, Johnson S: Immunosuppression with azathioprine and prednisone in recent-onset insulin-dependent diabetes mellitus. N Engl J Med 319:599–604, 1988 3045545
82 Harrison LC, Colman PG, Dean B, Baxter R, Martin FI: Increase in remission rate in newly diagnosed type I diabetic subjects treated with azathioprine. Diabetes 34:1306–1308, 1985 3905463
83 Cook JJ, Hudson I, Harrison LC, Dean B, Colman PG, Werther GA, Warne GL, Court JM: Double-blind controlled trial of azathioprine in children with newly diagnosed type I diabetes. Diabetes 38:779–783, 1989 2656346
84 Coutant R, Landais P, Rosilio M, Johnsen C, Lahlou N, Chatelain P, Carel JC, Ludvigsson J, Boitard C, Bougneres PF: Low dose linomide in type 1 juvenile diabetes of recent onset: a randomised placebo-controlled double blind trial. Diabetologia 41:1040–1046, 1998 9754822
85 Elliott JF, Marlin KL, Couch RM: Effect of bacille Calmette-Guerin vaccination on C-peptide secretion in children newly diagnosed with IDDM. Diabetes Care 21:1691–1693, 1998 9773732
86 Allen HF, Klingensmith GJ, Jensen P, Simoes E, Hayward A, Chase HP: Effect of Bacillus Calmette-Guerin vaccination on new-onset type 1 diabetes. A randomized clinical study. Diabetes Care 22:1703–1707, 1999 10526739
87 Chaillous L, Lefevre H, Thivolet C, Boitard C, Lahlou N, Atlan-Gepner C, Bouhanick B, Mogenet A, Nicolino M, Carel JC, Lecomte P, Marechaud R, Bougneres P, Charbonnel B, Sai P: Oral insulin administration and residual beta-cell function in recent-onset type 1 diabetes: a multicentre randomised controlled trial. Diabete Insuline Orale group. Lancet 356:545–549, 2000 10950231
88 Pozzilli P, Pitocco D, Visalli N, Cavallo MG, Buzzetti R, Crino A, Spera S, Suraci C, Multari G, Cervoni M, Manca Bitti ML, Matteoli MC, Marietti G, Ferrazzoli F, Cassone Faldetta MR, Giordano C, Sbriglia M, Sarugeri E, Ghirlanda G: No effect of oral insulin on residual beta-cell function in recent-onset type I diabetes (the IMDIAB VII). IMDIAB Group. Diabetologia 43:1000–1004, 2000 10990077
89 Ergun-Longmire B, Marker J, Zeidler A, Rapaport R, Raskin P, Bode B, Schatz D, Vargas A, Rogers D, Schwartz S, Malone J, Krischer J, Maclaren NK: Oral insulin therapy to prevent progression of immune-mediated (type 1) diabetes. Ann N Y Acad Sci 1029:260–277, 2004 15681764
90 Skyler JS, Lorenz TJ, Schwartz S, Eisenbarth GS, Einhorn D, Palmer JP, Marks JB, Greenbaum C, Saria EA, Byers V: Effects of an anti-CD5 immunoconjugate (CD5-plus) in recent onset type I diabetes mellitus: a preliminary investigation. The CD5 Diabetes Project Team. J Diabetes Complications 7:224–232, 1993 7693056
91 Herold KC, Hagopian W, Auger JA, Poumian-Ruiz E, Taylor L, Donaldson D, Gitelman SE, Harlan DM, Xu D, Zivin RA, Bluestone JA: Anti-CD3 monoclonal antibody in new-onset type 1 diabetes mellitus. N Engl J Med 346:1692–1698, 2002 12037148
92 Herold KC, Gitelman SE, Masharani U, Hagopian W, Bisikirska B, Donaldson D, Rother K, Diamond B, Harlan DM, Bluestone JA: A single course of anti-CD3 monoclonal antibody hOKT3gamma1(Ala-Ala) results in improvement in C-peptide responses and clinical parameters for at least 2 years after onset of type 1 diabetes. Diabetes 54:1763–1769, 2005 15919798
93 Keymeulen B, Vandemeulebroucke E, Ziegler AG, Mathieu C, Kaufman L, Hale G, Gorus F, Goldman M, Walter M, Candon S, Schandene L, Crenier L, De Block C, Seigneurin JM, De Pauw P, Pierard D, Weets I, Rebello P, Bird P, Berrie E, Frewin M, Waldmann H, Bach JF, Pipeleers D, Chatenoud L: Insulin needs after CD3-antibody therapy in new-onset type 1 diabetes. N Engl J Med 352:2598–2608, 2005 15972866
94 Keymeulen B, Walter M, Mathieu C, Kaufman L, Gorus F, Hilbrands R, Vandemeulebroucke E, Van de Velde U, Crenier L, De Block C, Candon S, Waldmann H, Ziegler AG, Chatenoud L, Pipeleers D: Four-year metabolic outcome of a randomised controlled CD3-antibody trial in recent-onset type 1 diabetic patients depends on their age and baseline residual beta cell mass. Diabetologia 53:614–623, 2010 20225393
95 Sherry N, Hagopian W, Ludvigsson J, Jain SM, Wahlen J, Ferry RJ, Jr., Bode B, Aronoff S, Holland C, Carlin D, King KL, Wilder RL, Pillemer S, Bonvini E, Johnson S, Stein KE, Koenig S, Herold KC, Daifotis AG; Protege Trial Investigators: Teplizumab for treatment of type 1 diabetes (Protege Study): 1-year results from a randomised, placebo-controlled trial. Lancet 378:487–497, 2011 21719095
96 Hagopian W, Ferry RJ, Jr., Sherry N, Carlin D, Bonvini E, Johnson S, Stein KE, Koenig S, Daifotis AG, Herold KC, Ludvigsson J; Protege Trial Investigators: Teplizumab preserves C-peptide in recent-onset type 1 diabetes: two-year results from the randomized, placebo-controlled Protege trial. Diabetes 62:3901–3908, 2013 23801579
97 Protege encore study—clinical trial of teplizumab (MGA031) in children and adults with recent-onset type 1 diabetes mellitus [article online], 2013. Available from https://clinicaltrials.gov/ct2/show/NCT00920582?term=NCT00920582. Accessed 3 December 2016
98 Aronson R, Gottlieb PA, Christiansen JS, Donner TW, Bosi E, Bode BW, Pozzilli P; DEFEND Investigator Group: Low-dose otelixizumab anti-CD3 monoclonal antibody DEFEND-1 study: results of the randomized phase III study in recent-onset human type 1 diabetes. Diabetes Care 37:2746–2754, 2014 25011949
99 Ambery P, Donner TW, Biswas N, Donaldson J, Parkin J, Dayan CM: Efficacy and safety of low-dose otelixizumab anti-CD3 monoclonal antibody in preserving C-peptide secretion in adolescent type 1 diabetes: DEFEND-2, a randomized, placebo-controlled, double-blind, multicentre study. Diabet Med 31:399–402, 2014 24236828
100 Herold KC, Gitelman SE, Ehlers MR, Gottlieb PA, Greenbaum CJ, Hagopian W, Boyle KD, Keyes-Elstein L, Aggarwal S, Phippard D, Sayre PH, McNamara J, Bluestone JA; the AbATE Study Team: Teplizumab (anti-CD3 mAb) treatment preserves C-peptide responses in patients with new-onset type 1 diabetes in a randomized controlled trial: metabolic and immunologic features at baseline identify a subgroup of responders. Diabetes 62:3766–3774, 2013 23835333
101 Herold KC, Gitelman SE, Willi SM, Gottlieb PA, Waldron-Lynch F, Devine L, Sherr J, Rosenthal SM, Adi S, Jalaludin MY, Michels AW, Dziura J, Bluestone JA: Teplizumab treatment may improve C-peptide responses in participants with type 1 diabetes after the new-onset period: a randomised controlled trial. Diabetologia 56:391–400, 2013 23086558
102 Ludvigsson J, Faresjo M, Hjorth M, Axelsson S, Cheramy M, Pihl M, Vaarala O, Forsander G, Ivarsson S, Johansson C, Lindh A, Nilsson NO, Aman J, Ortqvist E, Zerhouni P, Casas R: GAD treatment and insulin secretion in recent-onset type 1 diabetes. N Engl J Med 359:1909–1920, 2008 18843118
103 Wherrett DK, Bundy B, Becker DJ, DiMeglio LA, Gitelman SE, Goland R, Gottlieb PA, Greenbaum CJ, Herold KC, Marks JB, Monzavi R, Moran A, Orban T, Palmer JP, Raskin P, Rodriguez H, Schatz D, Wilson DM, Krischer JP, Skyler JS; Type 1 Diabetes TrialNet GAD Study Group: Antigen-based therapy with glutamic acid decarboxylase (GAD) vaccine in patients with recent-onset type 1 diabetes: a randomised double-blind trial. Lancet 378:319–327, 2011 21714999
104 Ludvigsson J, Krisky D, Casas R, Battelino T, Castano L, Greening J, Kordonouri O, Otonkoski T, Pozzilli P, Robert JJ, Veeze HJ, Palmer J: GAD65 antigen therapy in recently diagnosed type 1 diabetes mellitus. N Engl J Med 366:433–442, 2012 22296077
105 A phase III study to investigate the impact of Diamyd in patients newly diagnosed with type 1 diabetes (USA)—DIAPREVENT [article online], 2012. Available from https://clinicaltrials.gov/ct2/show/NCT00751842?term=NCT00751842. Accessed 3 December 2016
106 Raz I, Elias D, Avron A, Tamir M, Metzger M, Cohen IR: Beta-cell function in new-onset type 1 diabetes and immunomodulation with a heat-shock protein peptide (DiaPep277): a randomised, double-blind, phase II trial. Lancet 358:1749–1753, 2001 11734230
107 Raz I, Avron A, Tamir M, Metzger M, Symer L, Eldor R, Cohen IR, Elias D: Treatment of new-onset type 1 diabetes with peptide DiaPep277 is safe and associated with preserved beta-cell function: extension of a randomized, double-blind, phase II trial. Diabetes Metab Res Rev 23:292–298, 2007 17124720
108 Lazar L, Ofan R, Weintrob N, Avron A, Tamir M, Elias D, Phillip M, Josefsberg Z: Heat-shock protein peptide DiaPep277 treatment in children with newly diagnosed type 1 diabetes: a randomised, double-blind phase II study. Diabetes Metab Res Rev 23:286–291, 2007 17124721
109 Huurman VA, Decochez K, Mathieu C, Cohen IR, Roep BO: Therapy with the hsp60 peptide DiaPep277 in C-peptide positive type 1 diabetes patients. Diabetes Metab Res Rev 23:269–275, 2007 17024692
110 Schloot NC, Meierhoff G, Lengyel C, Vandorfi G, Takacs J, Panczel P, Barkai L, Madacsy L, Oroszlan T, Kovacs P, Suto G, Battelino T, Hosszufalusi N, Jermendy G: Effect of heat shock protein peptide DiaPep277 on beta-cell function in paediatric and adult patients with recent-onset diabetes mellitus type 1: two prospective, randomized, double-blind phase II trials. Diabetes Metab Res Rev 23:276–285, 2007 17103487
111 Raz I, Ziegler AG, Linn T, Schernthaner G, Bonnici F, Distiller LA, Giordano C, Giorgino F, de Vries L, Mauricio D, Prochazka V, Wainstein J, Elias D, Avron A, Tamir M, Eren R, Peled D, Dagan S, Cohen IR, Pozzilli P; DIA-AID 1 Writing Group: Treatment of recent-onset type 1 diabetic patients with DiaPep277: results of a double-blind, placebo-controlled, randomized phase 3 trial. Diabetes Care 37:1392–1400, 2014 24757230
112 Pozzilli P, Raz I, Peled D, Elias D, Avron A, Tamir M, Eren R, Dagan S, Cohen IR: Evaluation of long-term treatment effect in a type 1 diabetes intervention trial: differences after stimulation with glucagon or a mixed-meal. Diabetes Care 37:1384–1391, 2014 24408401
113 Raz I, Ziegler AG, Linn T, Schernthaner G, Bonnici F, Distiller LA, Giordano C, Giorgino F, de Vries L, Mauricio D, Prochazka V, Wainstein J, Elias D, Avron A, Tamir M, Eren R, Peled D, Dagan S, Cohen IR, Pozzilli P; DIA-AID 1 Writing Group: Retraction of: “Treatment of recent-onset type 1 diabetic patients with DiaPep277: results of a double-blind, placebo-controlled, randomized phase 3 trial. Diabetes Care 2014; 37:1392–1400.” Diabetes Care 38:178, 2015 24757230
114 Pozzilli P, Raz I, Peled D, Elias D, Avron A, Tamir M, Eren R, Dagan S, Cohen IR: Retraction of: “Evaluation of long-term treatment effect in a type 1 diabetes intervention trial: differences after stimulation with glucagon or a mixed meal. Diabetes Care 2014; 37:1384–1391.” Diabetes Care 38:179, 2015 24408401
115 Gottlieb PA, Quinlan S, Krause-Steinrauf H, Greenbaum CJ, Wilson DM, Rodriguez H, Schatz DA, Moran AM, Lachin JM, Skyler JS; Type 1 Diabetes TrialNet MMF/DZB Study Group: Failure to preserve beta-cell function with mycophenolate mofetil and daclizumab combined therapy in patients with new-onset type 1 diabetes. Diabetes Care 33:826–832, 2010 20067954
116 Pescovitz MD, Greenbaum CJ, Krause-Steinrauf H, Becker DJ, Gitelman SE, Goland R, Gottlieb PA, Marks JB, McGee PF, Moran AM, Raskin P, Rodriguez H, Schatz DA, Wherrett D, Wilson DM, Lachin JM, Skyler JS; The Type 1 Diabetes TrialNet Anti-CD20 Study Group: Rituximab, B-lymphocyte depletion, and preservation of beta-cell function. N Engl J Med 361:2143–2152, 2009 19940299
117 Pescovitz MD, Greenbaum CJ, Bundy B, Becker DJ, Gitelman SE, Goland R, Gottlieb PA, Marks JB, Moran A, Raskin P, Rodriguez H, Schatz DA, Wherrett D, Wilson DM, Krischer JP, Skyler JS; Type 1 Diabetes TrialNet Anti-CD20 Study Group: B-lymphocyte depletion with rituximab and β-cell function: two-year results. Diabetes Care 37:453–459, 2014 24026563
118 Orban T, Bundy B, Becker DJ, DiMeglio LA, Gitelman SE, Goland R, Gottlieb PA, Greenbaum CJ, Marks JB, Monzavi R, Moran A, Raskin P, Rodriguez H, Russell WE, Schatz D, Wherrett D, Wilson DM, Krischer JP, Skyler JS; Type 1 Diabetes TrialNet Abatacept Study Group: Co-stimulation modulation with abatacept in patients with recent-onset type 1 diabetes: a randomised double-blind, placebo-controlled trial. Lancet 378:412–419, 2011 21719096
119 Orban T, Bundy B, Becker DJ, DiMeglio LA, Gitelman SE, Goland R, Gottlieb PA, Greenbaum CJ, Marks JB, Monzavi R, Moran A, Peakman M, Raskin P, Russell WE, Schatz D, Wherrett DK, Wilson DM, Krischer JP, Skyler JS; Type 1 Diabetes TrialNet Abatacept Study Group: Costimulation modulation with abatacept in patients with recent-onset type 1 diabetes: follow-up 1 year after cessation of treatment. Diabetes Care 37:1069–1075, 2014 24296850
120 Moran A, Bundy B, Becker DJ, DiMeglio LA, Gitelman SE, Goland R, Greenbaum CJ, Herold KC, Marks JB, Raskin P, Sanda S, Schatz D, Wherrett DK, Wilson DM, Krischer JP, Skyler JS; Type 1 Diabetes TrialNet Canakinumab Study Group, Pickersgill L, de Koning E, Ziegler AG, Boehm B, Badenhoop K, Schloot N, Bak JF, Pozzilli P, Mauricio D, Donath MY, Castano L, Wagner A, Lervang HH, Perrild H, Mandrup-Poulsen T; the AIDA Study Group: Interleukin-1 antagonism in type 1 diabetes of recent onset: two multicentre, randomised double-masked, placebo-controlled trials. Lancet 381:1905–1915, 2013 23562090
121 Gitelman SE, Gottlieb PA, Rigby MR, Felner EI, Willi SM, Fisher LK, Moran A, Gottschalk M, Moore WV, Pinckney A, Keyes-Elstein L, Aggarwal S, Phippard D, Sayre PH, Ding L, Bluestone JA, Ehlers MR; START Study Team: Antithymocyte globulin treatment for patients with recent-onset type 1 diabetes: 12-month results of a randomised placebo-controlled, phase 2 trial. Lancet Diabetes Endocrinol 1:306–316, 2013 24622416
122 Rigby MR, DiMeglio LA, Rendell MS, Felner EI, Dostou JM, Gitelman SE, Patel CM, Griffin KJ, Tsalikian E, Gottlieb PA, Greenbaum CJ, Sherry NA, Moore WV, Monzavi R, Willi SM, Raskin P, Moran A, Russell WE, Pinckney A, Keyes-Elstein L, Howell M, Aggarwal S, Lim N, Phippard D, Nepom GT, McNamara J, Ehlers MR; T1DAL Study Team: Targeting of memory T cells with alefacept in new-onset type 1 diabetes (T1DAL study): 12 month results of a randomised, double-blind, placebo-controlled phase 2 trial. Lancet Diabetes Endocrinol 1:284–294, 2013 24622414
123 Rigby MR, Harris KM, Pinckney A, DiMeglio LA, Rendell MS, Felner EI, Dostou JM, Gitelman SE, Griffin KJ, Tsalikian E, Gottlieb PA, Greenbaum CJ, Sherry NA, Moore WV, Monzavi R, Willi SM, Raskin P, Keyes-Elstein L, Long SA, Kanaparthi S, Lim N, Phippard D, Soppe CL, Fitzgibbon ML, McNamara J, Nepom GT, Ehlers MR: Alefacept provides sustained clinical and immunological effects in new-onset type 1 diabetes patients. J Clin Invest 125:3285–3296, 2015 26193635
124 Orban T, Farkas K, Jalahej H, Kis J, Treszl A, Falk B, Reijonen H, Wolfsdorf J, Ricker A, Matthews JB, Tchao N, Sayre P, Bianchine P: Autoantigen-specific regulatory T cells induced in patients with type 1 diabetes mellitus by insulin B-chain immunotherapy. J Autoimmun 34:408–415, 2010 19931408
125 Long SA, Rieck M, Sanda S, Bollyky JB, Samuels PL, Goland R, Ahmann A, Rabinovitch A, Aggarwal S, Phippard D, Turka LA, Ehlers MR, Bianchine PJ, Boyle KD, Adah SA, Bluestone JA, Buckner JH, Greenbaum CJ; Diabetes TrialNet and the Immune Tolerance Network: Rapamycin/IL-2 combination therapy in patients with type 1 diabetes augments Tregs yet transiently impairs β-cell function. Diabetes 61:2340–2348, 2012 22721971
126 Gottlieb PA, Alkanani AK, Michels AW, Lewis EC, Shapiro L, Dinarello CA, Zipris D: α1-Antitrypsin therapy downregulates toll-like receptor-induced IL-1β responses in monocytes and myeloid dendritic cells and may improve islet function in recently diagnosed patients with type 1 diabetes. J Clin Endocrinol Metab 99:E1418–E1426, 2014 24527714
127 Walter M, Philotheou A, Bonnici F, Ziegler AG, Jimenez R; NBI-6024 Study Group: No effect of the altered peptide ligand NBI-6024 on beta-cell residual function and insulin needs in new-onset type 1 diabetes. Diabetes Care 32:2036–2040, 2009 19690081
128 Roep BO, Solvason N, Gottlieb PA, Abreu JR, Harrison LC, Eisenbarth GS, Yu L, Leviten M, Hagopian WA, Buse JB, von Herrath M, Quan J, King RS, Robinson WH, Utz PJ, Garren H; BHT-3021 Investigators, Steinman L: Plasmid-encoded proinsulin preserves C-peptide while specifically reducing proinsulin-specific CD8+ T cells in type 1 diabetes. Sci Transl Med 5:191ra82, 2013
129 Thrower SL, James L, Hall W, Green KM, Arif S, Allen JS, Van-Krinks C, Lozanoska-Ochser B, Marquesini L, Brown S, Wong FS, Dayan CM, Peakman M: Proinsulin peptide immunotherapy in type 1 diabetes: report of a first-in-man phase I safety study. Clin Exp Immunol 155:156–165, 2009 19040615
130 Haller MJ, Gitelman SE, Gottlieb PA, Michels AW, Rosenthal SM, Shuster JJ, Zou B, Brusko TM, Hulme MA, Wasserfall CH, Mathews CE, Atkinson MA, Schatz DA: Anti-thymocyte globulin/G-CSF treatment preserves β cell function in patients with established type 1 diabetes. J Clin Invest 125:448–455, 2015 25500887
131 Haller MJ, Gitelman SE, Gottlieb PA, Michels AW, Perry DJ, Schultz AR, Hulme MA, Shuster JJ, Zou B, Wasserfall CH, Posgai AL, Mathews CE, Brusko TM, Atkinson MA, Schatz DA: Antithymocyte globulin plus G-CSF combination therapy leads to sustained immunomodulatory and metabolic effects in a subset of responders with established type 1 diabetes. Diabetes 65:3765–3775, 2016 27669730
132 ATG-GCSF in new onset type 1 diabetes (ATG-GCSF) [article online], 2016. Available from https://clinicaltrials.gov/ct2/show/NCT02215200?term=02215200. Accessed 3 December 2016
133 Martin S, Herder C, Schloot NC, Koenig W, Heise T, Heinemann L, Kolb H; DIATOR Study Group: Residual beta cell function in newly diagnosed type 1 diabetes after treatment with atorvastatin: the randomized DIATOR trial. PLOS ONE 6:e17554, 2011 21412424
134 Strom A, Kolb H, Martin S, Herder C, Simon MC, Koenig W, Heise T, Heinemann L, Roden M, Schloot NC; DIATOR Study Group: Improved preservation of residual beta cell function by atorvastatin in patients with recent onset type 1 diabetes and high CRP levels (DIATOR trial). PLOS ONE 7:e33108, 2012 22448235
135 Mastrandrea L, Yu J, Behrens T, Buchlis J, Albini C, Fourtner S, Quattrin T: Etanercept treatment in children with new-onset type 1 diabetes: pilot randomized, placebo-controlled, double-blind study. Diabetes Care 32:1244–1249, 2009 19366957
136 Hartemann A, Bensimon G, Payan CA, Jacqueminet S, Bourron O, Nicolas N, Fonfrede M, Rosenzwajg M, Bernard C, Klatzmann D: Low-dose interleukin 2 in patients with type 1 diabetes: a phase 1/2 randomised, double-blind, placebo-controlled trial. Lancet Diabetes Endocrinol 1:295–305, 2013 24622415
137 Griffin KJ, Thompson PA, Gottschalk M, Kyllo JH, Rabinovitch A: Combination therapy with sitagliptin and lansoprazole in patients with recent-onset type 1 diabetes (REPAIR-T1D): 12-month results of a multicentre, randomised, placebo-controlled, phase 2 trial. Lancet Diabetes Endocrinol 2:710–718, 2014 24997559
138 Voltarelli JC, Couri CE, Stracieri AB, Oliveira MC, Moraes DA, Pieroni F, Coutinho M, Malmegrim KC, Foss-Freitas MC, Simoes BP, Foss MC, Squiers E, Burt RK: Autologous nonmyeloablative hematopoietic stem cell transplantation in newly diagnosed type 1 diabetes mellitus. JAMA 297:1568–1576, 2007 17426276
139 Couri CE, Oliveira MC, Stracieri AB, Moraes DA, Pieroni F, Barros GM, Madeira MI, Malmegrim KC, Foss-Freitas MC, Simoes BP, Martinez EZ, Foss MC, Burt RK, Voltarelli JC: C-peptide levels and insulin independence following autologous nonmyeloablative hematopoietic stem cell transplantation in newly diagnosed type 1 diabetes mellitus. JAMA 301:1573–1579, 2009 19366777
140 Voltarelli JC, Martinez EZ, Burt RK: Autologous nonmyeloablative hematopoietic stem cell transplantation in newly diagnosed type 1 diabetes mellitus. Author’s reply. JAMA 302:624–625, 2009
141 D’Addio F, Valderrama Vasquez A, Ben Nasr M, Franek E, Zhu D, Li L, Ning G, Snarski E, Fiorina P: Autologous nonmyeloablative hematopoietic stem cell transplantation in new-onset type 1 diabetes: a multicenter analysis. Diabetes 63:3041–3046, 2014 24947362
142 Tocilizumab (TCZ) in new-onset type 1 diabetes (EXTEND) [article online], 2017. Available from https://www.clinicaltrials.gov/ct2/show/NCT02293837. Accessed 3 December 2016
143 Investigation of otelixizumab in new-onset, autoimmune type 1 diabetes mellitus patients [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT02000817. Accessed 3 December 2016
144 Phase II-III study to evaluate the efficacy and safety of Glassia® in type-1 diabetes [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT02005848. Accessed 3 December 2016
145 Study of human plasma-derived alpha1-proteinase inhibitor in subjects with new-onset type 1 diabetes mellitus [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT02093221. Accessed 3 December 2016
146 Pilot clinical trial of ustekinumab in patients with new-onset T1D [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT02117765. Accessed 3 December 2016
147 Imatinib treatment in recent onset type 1 diabetes mellitus [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT01781975. Accessed 3 December 2016
148 Tauroursodeoxycholic acid (TUDCA) in new-onset type 1 diabetes [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT02218619. Accessed 3 December 2016
149 DIABGAD—trial to preserve insulin secretion in type 1 diabetes using GAD-alum (Diamyd) in combination with vitamin D and ibuprofen [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT01785108. Accessed 3 December 2016
150 Safety study to assess whether proinsulin peptide injections can slow or stop the body damaging its own insulin-making cells in the pancreas in patients newly diagnosed with type 1 diabetes [article online], 2015. Available from https://www.clinicaltrials.gov/ct2/show/NCT01536431. Accessed 3 December 2016
151 Effect of methyldopa on MHC class II antigen presentation in type 1 diabetes [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT01883804. Accessed 3 December 2016
152 Dose finding study of IL-2 at ultra-low dose in children with recently diagnosed type 1 diabetes (DFIL2-Child) [article online], 2016. Available from https://www.clinicaltrials.gov/ct2/show/NCT01862120. Accessed 3 December 2016
153 Skyler JS: Prevention and reversal of type 1 diabetes—past challenges and future opportunities. Diabetes Care 38:997–1007, 2015 25998292