# CHAPTER 35 Mortality in Type 1 Diabetes

## Summary

Despite major advances in management and care, type 1 diabetes remains associated with considerable premature mortality. Although significant improvements in life expectancy have been observed in those diagnosed since 1965, mortality rates among patients with type 1 diabetes remain significantly higher than the general population, a finding confirmed by several studies in the United States and internationally, with standardized mortality ratios revealing that patients with type 1 diabetes have mortality rates that are 3–18 times higher than would be expected in their respective countries. There is marked geographic variation in mortality, and further notable differences between males and females, compared to the general population.

Deaths due to diabetes-related acute and chronic complications appear to account for nearly all of the excess premature mortality in patients with type 1 diabetes compared to the general population. Diabetes-related chronic complications, particularly cardiovascular and renal disease, are now the predominant causes of death in type 1 diabetes, in contrast to the high rates of death due to diabetes-related acute complications (i.e., glycemic-related events) observed during earlier years (i.e., the pre-insulin era). End-stage renal disease (ESRD), historically, is the leading cause of death in the mid-years of diabetes duration (up to 35 years), accounting for more than half of deaths. After 35 years duration, however, cardiovascular disease (CVD) is the leading cause of death, accounting for two-thirds of deaths. With the decline (or delay) in developing ESRD due to improvements in diabetes management, this pattern may be changing.

Several risk factors for type 1 diabetes mortality have been investigated. Females with type 1 diabetes continue to have a greater increase in mortality compared to females in the general population than is found for males. This pattern is consistent for all causes of death, particularly CVD, where the standardized mortality ratio for females (24.7) is nearly three times that for males (8.6), primarily resulting from the lower rates of mortality in the female general population. In addition, African Americans remain at increased risk of premature mortality compared to Caucasians, consistently having mortality rates 2.5 higher than their Caucasian counterparts over the past 30 years. Onset of type 1 diabetes after puberty also appears to be associated with 1.5–2.0-fold higher mortality than prepubertal onset. Several other factors are associated with type 1 diabetes mortality, including lower socioeconomic status, hypertension, smoking, and renal failure. Some risk factors, such as glycemic control and insulin resistance, have not consistently shown direct associations with type 1 diabetes mortality but are associated with diabetes-related chronic complications and are likely contributing factors. Indeed, the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study suggests that even 6 years of more intensive therapy may lead to a lower mortality over 20 years of further follow-up.

Finally, type 1 diabetes has a greater impact on mortality rates in U.S. populations than seen in many European countries, with U.S. standardized mortality ratios of 6.9–7.5 compared to European standardized mortality ratios of 3.3–4.2. These geographic differences indicate an urgent need to improve disease management and access to care in the United States.

## Introduction

Historically, type 1 diabetes has been associated with a greatly increased risk of early mortality. Fortunately, this is no longer necessarily the case, and many individuals with type 1 diabetes can expect a normal lifespan. This chapter reviews type 1 diabetes mortality from a variety of perspectives, including improvements in mortality and life expectancy over time and comparisons to the general U.S. population, as well as international type 1 diabetes populations. Major studies and registries are described, and data are presented regarding causes of death and predictors/risk factors for mortality.

## Historical Data (Pre-1980 Era)

Prior to the availability of insulin in bovine form in 1922, dietary restrictions and supportive therapies could usually only delay mortality for 1–2 years after onset of type 1 diabetes. Based on mortality data from the Joslin Clinic in Boston, Massachusetts, the mortality rate for type 1 diabetes patients dying within the first 10 years of life improved dramatically from 824 per 1,000 in 1897–1914 to 386 per 1,000 in 1914–1922 down to 61 per 1,000 in 1922–1926, a sixfold reduction immediately after bovine insulin became available (Figure 35.1) (1). As more standardized treatment plans were developed, these mortality rates continued to decline to 1 per 1,000 in 1950–1961 (1).

Other diabetes clinics reported that their type 1 diabetes mortality rates during the 1920s and 1930s ranged from 30% to 50% for patients diagnosed in the 1920s and followed for at least 20 years, with little difference observed by sex (2,3). Acute diabetes complications like ketoacidosis or hypoglycemia were relatively common, accounting for 15%–40% of all type 1 diabetes deaths during the 1920s at various clinics (1,2,4). With improvements in diagnosis and care, acute complications quickly became rare at these clinics, accounting for <5% of all type 1 diabetes deaths by 1943 (1,2). By the 1950s and 1960s, Joslin Clinic was reporting that diabetic comas accounted for 1% or less of all deaths in its patients, with the proportion of deaths due to diabetic coma declining by age (Figure 35.2) (1,5,6).

Prior to the discovery of antibiotics in the 1940s, infections accounted for a substantial proportion (10%–20%) of all deaths, but this figure dropped to 5%–6% after antibiotic use became widespread (1). In the 1950s, the role of long-term diabetic complications (i.e., renal disease, cardiovascular disease [CVD], hypertension, and neuropathy) on mortality became apparent, as data from long-term follow-up studies began to accumulate on patients with ≥30 years duration of diabetes (1,7,8). Although many patients with type 1 diabetes were now surviving well into adulthood with insulin therapy, their lifespans remained significantly shorter than the general population due to frequent diabetes-related complications (1). A Joslin Clinic study found that after 35 years of diabetes duration, CVD was the leading cause of death (9) and accounted for nearly 65% of all type 1 diabetes deaths by the early 1960s (1). Another Joslin report showed that the proportion of deaths caused by combined CVD and renal disease tripled by the 1960s compared to the pre-insulin era (76.6% vs. 24.6%) (Figure 35.3) (10).

FIGURE 35.1 Mortality Prior to Age 10 Years Among Patients With Type 1 Diabetes, Joslin Clinic, Boston, Massachusetts, 1897–1961

Bar chart showing that the mortality rate improved from 386 per 1,000 in 1914-1922 to 61 per 1,000 in 1922-1926, a sixfold reduction after bovine insulin became available in 1922.

SOURCE: Reference 1

FIGURE 35.2 Cause-Specific Mortality in Type 1 Diabetes by Age at Death, Joslin Clinic, Boston, Massachusetts, 1956–1962

Type 1 diabetes is defined as diagnosis prior to age 20 years.

* Includes diabetic ketoacidosis or hypoglycemia.

† Includes cerebrovascular disease and diabetic gangrene.

‡ Includes cancer, violence, other, and unknown.

Pie charts showing that by the 1950s and 1960s, diabetic comas accounted for 1% or less of all deaths in type 1 diabetes patients, with the proportion declining by age.

SOURCE: Reference 1

FIGURE 35.3 Proportional Mortality Due to Cardiovascular-Renal Disease in Type 1 Diabetes, Joslin Clinic, Boston, Massachusetts, 1897–1968

Bar chart showing that the proportion of deaths among type 1 diabetes patients due to cardiovascular disease or renal disease tripled by the 1960s compared to the pre-insulin era.

SOURCE: Reference 10

During this pre-1980 era, cohorts of individuals who purchased or applied for life insurance policies were used to explore type 1 diabetes mortality. A 1967 study did not differentiate type 1 from type 2 diabetes; however, looking only at those diagnosed by age 30 years between 1935 and 1963, a sixfold greater mortality existed compared to that expected based on the nondiabetic population of policyholders, with excess mortality largely due to CVD (11). Using life insurance applicants between 1950 and 1971, those diagnosed with diabetes prior to age 15 years had an elevenfold increase in mortality compared to that expected based on nondiabetic applicants, with a calculated life expectancy of 32 years for those with type 1 diabetes (12,13).

Joslin Clinic was an early leader in type 1 diabetes mortality research in the United States due to its large clinic population. However, as a world-renowned clinic, the clinic population was not representative of type 1 diabetes in the United States. To decrease selection bias, Joslin Clinic studies limited inclusion to Massachusetts residents seen at the clinic within 1 year of diagnosis and estimated mortality rates at 2–14 times higher than the general population, with extremely high mortality rates after age 35 years (1,5,14,15). These mortality rates may still be subject to patient selection bias and a failure to distinguish between type 1 and type 2 diabetes in the older age groups.

Population-based early type 1 diabetes mortality data first came from Erie County (Buffalo), New York (16). In an analysis of all major childhood diseases, these researchers examined hospital, specialist, vital, and school records to ascertain childhood diseases, including type 1 diabetes, in all persons age <16 years diagnosed between 1946 and 1961. They found 389 persons with type 1 diabetes. Only seven deaths occurred during the study period, with higher case-fatality rates in females, low income, and nonwhite type 1 diabetic persons. The overall mortality rate was 4.1 per 1,000 patient-years (16). Compared to other childhood diseases in the same population, diabetes mortality was fourfold higher than that of asthma (1.0 per 1,000 person-years), but significantly lower than that of cystic fibrosis (139.4 per 1,000 person-years).

In summary, the findings of these early studies showed dramatic improvements in overall type 1 diabetes mortality with the pattern shifting from mostly acute complications in the 1920s and 1930s to mostly chronic diabetes complications since the 1940s.

## Current (Post-1980) Era

During the 1980s, a major shift in type 1 diabetes research occurred. A number of large, population-based type 1 diabetes registries and cohort studies were developed to assess geographic variations in type 1 diabetes incidence both within the United States and internationally. These registry and cohort populations, as well as key mortality-related research findings, are summarized below.

### Key Findings

#### Pittsburgh Registries

Two early efforts to obtain representative cohorts came from the Pittsburgh, Pennsylvania, area in the 1980s, specifically the Children’s Hospital of Pittsburgh (CHP)-based type 1 diabetes registry and the population-based Allegheny County Type 1 Diabetes Registry (ACR) (17,18,19). The former was the source of the Pittsburgh Epidemiology of Diabetes Complications (EDC) study, while the latter was the U.S. cohort in the Diabetes Epidemiology Research International (DERI) study. Demographic characteristics between the registries were similar (18,19). Based on 1,966 individuals diagnosed with type 1 diabetes at CHP between 1950 and 1981, mortality among type 1 diabetes patients in the hospital-based registry compared to that expected for the U.S. population of the same age ranged from 5.4 times higher for males with type 1 diabetes to 11.5 times higher for females with type 1 diabetes (Figure 35.4) (17). Mortality rates were most dramatic in type 1 diabetic persons age >25 years, where >2% died annually, which translated into a mortality rate approximately 20 times higher than the general U.S. population (20). Early ACR findings also showed that although Caucasian children with type 1 diabetes had mortality rates 1.5 times higher than African American children without diabetes, African Americans with diabetes had 2.4 times the risk of early type 1 diabetes mortality compared to Caucasians (21). The EDC study, derived from the CHP registry, reported a remarkable decline in mortality and renal disease between those diagnosed in the 1950s and 1960s compared to those diagnosed in the in 1970s and 1980s (22). These and more recent data from the ACR are discussed in the Causes of Death in Type 1 Diabetes section.

FIGURE 35.4 Observed Deaths of Type 1 Diabetes Patients Diagnosed (Age ≤16 Years) at Children’s Hospital of Pittsburgh Between 1950 and 1981 Compared to That Expected in the General U.S. Population

Bar chart showing that mortality among type 1 diabetes patients was 5 to 12 times higher compared to that expected for the U.S. population of the same sex and age.

SOURCE: Reference 17, copyright © 1984 American Diabetes Association, reprinted with permission

#### Wisconsin Study

The Wisconsin Epidemiologic Study of Diabetic Retinopathy (WESDR) began in 1979 with diabetic individuals being identified in 11 counties in southern Wisconsin (23). This cohort included 996 individuals with presumed type 1 diabetes (defined as age of diagnosis <30 years and on insulin therapy). In a 20-year follow-up report, 64% of deaths involved heart disease, and retinopathy and nephropathy status significantly predicted cardiovascular mortality (24). A separate analysis showed a significant association between mortality and hyperglycemia. Compared to the lowest quartile, participants in the highest glycosylated hemoglobin (A1c) quartile had a higher risk of overall mortality (relative risk 2.4, 95% confidence interval [CI] 1.5–3.8) (25).

#### Joslin Studies

The Joslin Clinic in Boston has long been a leader in diabetes epidemiology using its large database of diabetes patients. Early reports from Joslin are described in the Historical Data section. In 2008, a study from Joslin Clinic described an association between mortality and self-reported insulin restriction in women with type 1 diabetes, in an effort to lose weight, often due to eating disorder problems. There was a threefold increase in mortality in type 1 diabetic women reporting self-induced insulin restriction (50% of the population studied), after adjusting for age, body mass index (BMI), and A1c level, highlighting an understudied area of dramatically higher mortality in women with type 1 diabetes suffering from eating disorders (26). Women with type 1 diabetes and concomitant anorexia nervosa have remarkably higher risks of mortality (standardized mortality ratio ≥14.5) (27,28). Eating disorders in women are discussed in more detail in Chapter 33 Psychiatric and Psychosocial Issues Among Individuals Living With Diabetes.

TABLE 35.1 Death Rate for Deaths Coded to Diabetes on U.S. Death Certificates, by Age of Death, 1950–2009

YEAR | AGE (YEARS)
YEAR | <5 | 5–9 | 10–14 | 15–19 | 20–24 | 25–29
1950–1954 | 4.0 | 3.6 | 6.6 | 10.0 | 12.6 | 19.8
1955–1959 | 3.0 | 2.5 | 5.0 | 7.0 | 12.5 | 20.1
1960–1964 | 2.6 | 2.2 | 4.2 | 5.8 | 10.7 | 21.4
1965–1969 | 2.2 | 1.8 | 3.4 | 4.1 | 9.9 | 19.8
1970–1974 | 2.0 | 1.5 | 2.5 | 3.7 | 7.8 | 15.9
1975–1979 | 1.0 | 0.9 | 1.5 | 2.2 | 5.6 | 11.9
1980–1984 | 0.9 | 0.8 | 1.3 | 1.7 | 4.5 | 10.5
1985–1989 | 0.7 | 0.7 | 1.1 | 1.8 | 4.6 | 10.4
1990–1994 | 0.5 | 0.5 | 0.9 | 1.8 | 4.9 | 11.2
1995–1999 | 0.4 | 0.4 | 0.8 | 2.3 | 5.4 | 10.8
2000–2004 | 0.4 | 0.4 | 1.2 | 2.4 | 5.6 | 11.0
2005–2009 | 0.4 | 0.4 | 1.1 | 2.4 | 6.1 | 10.8

Death rates per 1,000,000 people.

SOURCE: National Vital Statistics Reports, 1950–2009

FIGURE 35.5 Annual Death Rates in Childhood From Diabetes Per 1 Million Persons Age ≤19 Years, U.S., 1968–2009

Error bars represent 95% confidence intervals.

Dot chart showing that diabetes-related mortality prior to age 20 decreased 61%, from 2.7 deaths per million per year in 1968 to 1969 to 1.0 deaths per million per year in 2008 to 2009.

SOURCE: Reference 31

#### New Jersey 725

The New Jersey 725 Study examined mortality rates in 725 African Americans with a mean type 1 diabetes duration of 8 years. Participants were randomly selected from a population of hospitalized African Americans with a discharge diagnosis of diabetes, who were diagnosed prior to age 30 years and treated with insulin. Three-year mortality rates were 7.1% for women and 10.6% for men (29). More data from this study are presented in the Mortality by Race section.

FIGURE 35.6 Cumulative Mortality by Diagnosis Year and Duration of Type 1 Diabetes: The Pittsburgh Epidemiology of Diabetes Complications Study

Bar chart showing that the cumulative mortality after 25 years duration of type 1 diabetes declined from 35% for those diagnosed in the 1950s to 7% for those diagnosed in the early 1970s.

SOURCE: Reference 22, copyright © 2006 American Diabetes Association, reprinted with permission

FIGURE 35.7 Life Expectancy at Birth by Diagnosis Cohort Based on Pittsburgh Type 1 Diabetes Registries

Error bars represent 95% confidence intervals.

* Pittsburgh Epidemiology of Diabetes Complications Study

Bar chart showing that life expectancy for the Allegheny County Registry diagnosed between 1965 and 1979 was 67 years, which was comparable to the Pittsburgh E D C study.

SOURCE: Reference 36, copyright © 2012 American Diabetes Association, reprinted with permission

### Temporal Trends in Mortality

Analyses conducted for Diabetes in America, 3rd edition, based on U.S. death certificates with diabetes listed as the underlying cause of death yielded diabetes-specific death rates (per 1,000,000 population) (Table 35.1). Between 1950 and 2009, there has been a marked downward trend in type 1 diabetes mortality, which appears to have leveled off during the 1990s. This trend likely reflects improvements in type 1 diabetes care, as incidence of type 1 diabetes is increasing in the United States (30). A Centers for Disease Control and Prevention analysis of diabetes-related mortality prior to age 20 years showed a decrease of 61% (2.7 deaths per million per year in 1968–1969 vs. 1.0 deaths per million per year in 2008–2009) (Figure 35.5) (31). Children age <10 years with type 1 diabetes showed a more significant decline in mortality than those age 10–19 years (78% vs. 52%, respectively).

In the Pittsburgh EDC study, at 25 years duration of type 1 diabetes, cumulative mortality declined by 80% from 35% for those diagnosed in the 1950s to 7% for those diagnosed in the early 1970s (Figure 35.6) (22).

#### Improvements in Life Expectancy

As discussed, life expectancy for type 1 diabetes improved dramatically after the discovery of insulin as an effective therapy in the 1920s. Both the Joslin Clinic and the Steno Clinic showed type 1 diabetes life expectancy to increase by 15 years between 1933 and 1972 (1,32,33,34).

Despite these improvements in treatment, a report from 1975 using a life insurance cohort still found life expectancy in type 1 diabetes (diagnosis age <15 years) to be reduced 27 years compared to individuals without diabetes (13). Data from the National Health Interview Surveys from 1984–2000 showed that U.S. children diagnosed with diabetes at age 10 years lose approximately 19 years of life (35).

Based on 30 years of longitudinal data, the Pittsburgh EDC study showed that life expectancy (from birth) increased by approximately 15 years for those diagnosed in 1965–1980 compared to those diagnosed in 1950–1964 (68.8 years vs. 53.4 years, respectively, p<0.0001) (36). Over the same time interval, life expectancy for the comparable cohort of the general U.S. population increased by <1 year (36). Life expectancy for the ACR (diagnosed 1965–1979) was 67.2 years, which was comparable to the 1965–1980 EDC diagnosis subcohort (Figure 35.7).

### Comparisons to the General Population

Standardized mortality ratios, which compare the observed number of deaths in a specific cohort (e.g., individuals with type 1 diabetes) to that expected (usually a local general population over the same time period), are uniformly increased in type 1 diabetes. An early report, examining only black type 1 diabetes patients at two U.S. diabetes clinics (Memphis, Tennessee, and Atlanta, Georgia), found a twofold excess in mortality compared to the general black population in 1970–1971 (37). In Wisconsin, type 1 diabetic males and females had a sevenfold and ninefold greater mortality risk compared to the general Wisconsin population, respectively (38). African American males and females with type 1 diabetes in New Jersey had a sixfold and twelvefold greater risk, respectively, compared to the general New Jersey population (29). Standardized mortality ratios that have been age- and sex-standardized have been calculated periodically in the ACR. In the early 1980s, the standardized mortality ratios for those diagnosed prior to 1975 was significantly higher than for those diagnosed in the late 1970s (39). A 2008 follow-up of the same cohort showed that males and females with type 1 diabetes had fivefold and thirteenfold higher numbers of deaths, respectively, than would be expected in the general Allegheny County population (40). The same analysis showed a significant temporal improvement in standardized mortality ratios by diagnosis year (Figure 35.8).

### Key Demographic Variables

#### Mortality by Age at Onset

The effect of prepubertal (age <11 years in girls and <12 years in boys) or peripubertal age of onset of type 1 diabetes was noted in early studies in the CHP cohort (41). This effect was also noted in studies in Finland and Japan, where Cox proportional hazard models indicated that individuals diagnosed during or after puberty were at higher risk of death than those diagnosed at a prepubertal age (Table 35.2) (40,42). However, the effect diminishes after adjusting for the mortality rates of the general population. Similarly, a modest effect was noted in the ACR cohort; however, there were no clear patterns in the standardized mortality ratios estimated by age at onset (40). This phenomenon of later age of diagnosis conferring increased risk for mortality supports earlier suggestions that the prepubertal years are relatively benign (43,44). This may also, in part, be explained by who manages type 1 diabetes: the parent in childhood and the individual with type 1 diabetes during the teenage and young adult years.

#### Mortality by Sex

Sex-specific differences in type 1 diabetes mortality are clear. Females with type 1 diabetes consistently have higher standardized mortality ratios than their male counterparts (Figure 35.9) (38,40,42,45,46,47). The magnitude of the sex difference in mortality is marked and confirms that any sex advantage for mortality seen for women in the general population is lost in type 1 diabetes (48,49). Cause-specific analyses found that sex-specific standardized mortality ratios for CVD deaths in the ACR cohort were 8.6 for males and 24.7 for females. In fact, females have higher standardized mortality ratios for all diabetes-related causes of death (acute complications, CVD, renal disease, and infections) compared to males. The reasons for these differences are unclear but probably reflect both relatively low rates of some causes (e.g., CVD) in females in the general population and higher rates of others (e.g., acute complications) in diabetic female youth (50). While males with type 1 diabetes have an accident/suicide mortality rate seven times higher than females with type 1 diabetes, the standardized mortality ratios for violent deaths were not significantly different from the general population for either sex, similar to type 1 diabetes findings in Europe (51,52).

FIGURE 35.8 Standardized Mortality Ratios Assessed in 1980 and 2008, Allegheny County Type 1 Diabetes Registry

* Life-tables for comparison are based on general U.S. mortality data.

† Life-tables for comparison are based on general Allegheny County mortality data.

Bar chart showing a significant temporal improvement in standardized mortality ratios by diagnosis year.

SOURCE: References 39 and 40

TABLE 35.2 Comparison of Mortality Rates by Age at Onset in Different Type 1 Diabetes Populations

POPULATION, YEARS (REF.) | FOLLOW-UP (YEARS) | MORTALITY RATE PER 100,000 PERSON-YEARS (95% CONFIDENCE INTERVAL)
POPULATION, YEARS (REF.) | FOLLOW-UP (YEARS) | Prepubertal; (Males <12 years \| Females <11 years) | Pubertal; (Males ≥12 years \| Females ≥11 years)
Allegheny County, 1965–2007 (41) | 30 | 685 (564–805) | 954 (803–1,104)
Japan, 1965–1994 (43) | 15 | 456 (356–576) | 941 (728–1,197)
Finland, 1965–1994 (43) | 15 | 278 (234–328) | 446 (383–516)

SOURCE: References are listed within the table.

FIGURE 35.9 Standardized Mortality Ratios in Type 1 Diabetes Studies

Error bars represent 95% confidence intervals.

* Based on 8.5 years of follow-up (1980–1988).

† Based on 16.3 mean years of follow-up (1965–1994).

‡ Based on 17.8 mean years of follow-up (1965–1994).

§ Based on 29 years of follow-up (1972–2000).

‖ Based on 24.2 mean years of follow-up (1973–2002).

¶ Based on 28 years of follow-up (1965–2007).

Bar chart showing that sex-specific standardized mortality ratios for type 1 diabetes were higher in females compared to males.

SOURCE: References 38, 40, 42, 45, 46, and 47

TABLE 35.3 Mortality Rates by Race, Allegheny County Type 1 Diabetes Registry Cohort and Chicago Type 1 Diabetes Registry Cohort

STUDY NAME, YEARS (REF.) | DEATH RATES PER 100,000 PERSON-YEARS (95% CONFIDENCE INTERVAL)
STUDY NAME, YEARS (REF.) | Caucasians | African Americans
Allegheny County Registry, 1965–1989 (53) | 380 (240–480) | 910 (340–1,480)
Allegheny County Registry, 1965–1998 (54) | 571 (478–672) | 1,388 (895–2,012)
Allegheny County Registry, 1965–1999 (48) | 492 (412–573) | 1,318 (1,168–1,469)
Chicago Registry, 1985–2000 (55) | 48 (6–174) | 448 (284–672)
Allegheny County Registry, 1965–2007 (40) | 742 (648–836) | 1,851 (1,278–2,425)

SOURCE: References are listed within the table.

FIGURE 35.10 Standardized Mortality Ratios in African Americans With Type 1 Diabetes

Error bars represent 95% confidence intervals.

* Based on 3 years of follow-up (1999–2001).

† Based on 28 years of follow-up (1965–2007).

‡ Based on 19 years of follow-up (1979–2010).

Bar chart showing elevated standardized mortality ratios among African Americans with type 1 diabetes compared to African Americans in the general population.

SOURCE: References 29, 40, and 57

#### Mortality by Race

Many studies have indicated that racial differences exist in type 1 diabetes mortality. Mortality rates in the ACR at different follow-up periods are presented by race in Table 35.3 (40,48,53,54,55). Similarly, a study of young Chicago, Illinois, patients showed that African Americans were at nearly tenfold increased risk of early mortality (age <25 years) compared to Caucasians (56). Interestingly, despite persistent 2.5-fold differences in overall mortality in the ACR by race, standardized mortality ratios were similar for African Americans with type 1 diabetes and Caucasians with type 1 diabetes (7.5 vs. 7.4, respectively) compared to the general population (40). This phenomenon may be partly explained by higher background mortality in younger African Americans in the general population due to accidental and violent causes and the surprising absence of these causes of death in African Americans with type 1 diabetes in Allegheny County. These elevated standardized mortality ratios among African Americans with type 1 diabetes compared to African Americans in the general population are seen not only in the ACR, but also in New Jersey and the U.S. Virgin Islands (Figure 35.10) (29,40,57).

Little information exists on long-term cause-specific mortality for African Americans with type 1 diabetes. A retrospective study of death certificates for Chicago residents (age 1–24 years) showed all eight acute complication deaths at onset (of 30 total type 1 diabetes deaths) occurred in either non-Hispanic black (seven) or Hispanic (one) patients (56). Caucasian type 1 diabetic patients accounted for only two deaths during this interval in Chicago, and neither was due to acute complications. African Americans with type 1 diabetes have significantly higher mortality rates for all diabetes-related complications compared to Caucasians with type 1 diabetes (50). This poorer prognosis for African Americans with type 1 diabetes reflects the ongoing racial gap in socioeconomic status or access to and utilization of health care in the United States (58).

### Causes of Death in Type 1 Diabetes

#### Limitations of Death Certificates

Epidemiologic studies have long relied on death certificates to obtain mortality data, specifically data relating to the cause(s) of death. A notable Swedish study in 1976 used registry data to validate the cause of death listed on 1,156 death certificates and found that the death certificates were valid for most forms of cancer, stroke, and respiratory disease but not for diabetes (59). In the United States, misclassification, as well as substantial underreporting of mortality from diabetes, is also prevalent (60).

Only one study from Germany has specifically examined the reliability of the cause of death on death certificates in individuals with type 1 diabetes (61). A mortality review committee found that only 25% of hypoglycemic deaths were listed as such on the death certificate, and similarly, only 57% of deaths from diabetic ketoacidosis (DKA) actually listed DKA on the death certificate (61). The committee only agreed with death certificates when the cause of death was not diabetes-related (i.e., cancer, myocardial infarction, stroke, or accident). The discrepancies result both from significant overlap between complications in type 1 diabetes (e.g., CVD and renal disease) and from the lack of formal training for physicians on death certificate completion. Thus, death certificates alone are not reliable when determining the true clinical outcome of deceased type 1 diabetes patients.

#### DERI Mortality Classification

Understanding the limitations of death certificates, a standardized protocol with a Mortality Classification Committee has been developed for determining underlying and secondary causes of death based not only death certificates, but also any other available data—medical records, autopsy/coroner’s reports, and interviews with next-of-kin (39). Key findings from this standardized international effort are described in the United States Compared to Other Countries section. The DERI classification was used in many studies (4,28,34,46,49,50,53,54,57,62,63,64,65,66,67,68,69), including in the Diabetes Control and Complications Trial (DCCT)/Epidemiology of Diabetes Interventions and Complications (EDIC) study (70). Aside from the population-based cohorts in the DERI Study Group (Allegheny County, Finland, Israel, and Japan), few type 1 diabetes cohorts have examined mortality thoroughly using a physician-based review committee (47,70,71).

#### Complication-Specific Findings

The higher mortality seen in type 1 diabetes compared to the general population results almost exclusively from higher rates of diabetes-related acute and chronic complications. Females with type 1 diabetes in the United States have higher mortality rates for early acute complications (<10 years diabetes duration); whereas, males with type 1 diabetes have higher mortality rates for accidental or violent (non-diabetes) deaths (Figure 35.11, Panel A) (50,72). Mortality rates for all major diabetes-related complications (acute, renal, cardiovascular, and infectious) are significantly higher in African Americans with type 1 diabetes compared to Caucasians with type 1 diabetes (Figure 35.11, Panel B) (50,72). No significant changes in cause-specific distributions have been observed in those diagnosed with diabetes more recently (1970s) compared to those diagnosed in the 1960s (Figure 35.11, Panel C) (50,72).

FIGURE 35.11 Distribution of Underlying Causes of Death by Duration of Diabetes and Sex (A), Race (B), and Diabetes Diagnosis Cohort (C), Allegheny County, Pennsylvania, 1965–2007

Panel A bar chart showing that females with type 1 diabetes for less than 10 years in duration have higher mortality rates for acute complications; males have higher mortality rates for non-diabetes deaths. Panel B bar chart showing that mortality rates for all major diabetes-related complications are higher in African Americans compared to Caucasians with type 1 diabetes. Panel C bar chart showing that no changes in cause-specific mortality distributions occurred in those diagnosed in the 1970s compared to the 1960s.

Underlying causes of death were divided into acute diabetes complications (e.g., hypoglycemia, diabetic ketoacidosis), chronic diabetes complications (e.g., cardiovascular disease, renal disease, infections), and non-diabetes (e.g., accidents, violence).

SOURCE: Reference 50, copyright © 2010 American Diabetes Association, reprinted with permission; and Reference 72

Causes of early type 1 diabetes mortality (<10 years diabetes duration) have been extensively studied in many cohorts. A report from the CHP cohort showed that 64% of all deaths in childhood-onset type 1 diabetes within the first 11 years after diagnosis were caused by acute complications (all DKA) (73) compared to 74% from the ACR in the first 10 years. An international study found acute complications (38%) to be the leading cause of death in the first 10 years of type 1 diabetes, followed by accident/suicide (30%), with acute deaths occurring more commonly in the United States and Japan compared to Finland and Israel (39). Acute complications contributed to 93% of deaths in females and 40% in males within the first 10 years after diabetes diagnosis, a sex difference explained at least in part by the increased risk of violent/accidental deaths in young males (Figure 35.12, Panel A) (50,72).

Only a handful of studies have evaluated cause-specific mortality in longstanding type 1 diabetes (>20 years duration). Steno Clinic tracked all individuals diagnosed with type 1 diabetes (age ≤30 years) before 1943 and followed them until death or January 1, 1984. CVD accounted for two-thirds of all deaths after 40 years of type 1 diabetes but only one-fourth of all deaths before 35 years duration. However, CVD currently contributes to more than half of all deaths after 20 years of diabetes, with many of these deaths occurring in individuals with concomitant renal disease (Figure 35.12, Panel B) (50,72). Similar findings from the Diabetes U.K. study (N=23,752) showed that acute complications accounted for 34% of all deaths prior to age 30 years, but thereafter, CVD became the leading cause (52%) (74). Conversely, end-stage renal disease (ESRD) accounted for >50% of deaths within 35 years duration of type 1 diabetes compared to only 5% of deaths after 40 years duration (75). For comparison, ESRD was the underlying cause of death in only 17% of deaths (50, A. Secrest, T. Orchard, personal communication) but contributed to nearly 50% (i.e., including secondary causes of death, usually with CVD as the primary cause of death) of those who died after 10 years duration of type 1 diabetes in the ACR (Figure 35.12, Panel C) (50,72). Diabetes management appears to be delaying or preventing some ESRD, but there is significant room for improvement. The DCCT/EDIC findings (70) suggest intensive therapy may have a small benefit on mortality from all causes except accidents, suicides, and acute complications. The relationship to intensity of therapy and glycemic control is discussed in the Risk Factors for Mortality section.

FIGURE 35.12 Total Contribution of Major Diabetes Complications to Deaths in Type 1 Diabetes, by Sex and Duration of Diabetes, Allegheny County, Pennsylvania, 1965–2007

Panel A bar chart showing that acute complications contributed to 93% of deaths in females and 40% in males within 10 years after diabetes diagnosis. Panel B bar chart showing that cardiovascular disease contributed to more than half of all deaths after 20 years of diabetes. Panel C bar chart showing that end-stage renal disease contributed to nearly 50% of those who died after 10 years duration of type 1 diabetes, including secondary causes of death.

Data represent the proportion of deaths for which the following complications either caused or contributed to death: acute complications (A), cardiovascular disease (B), and end-stage renal disease (C).

SOURCE: Reference 50, copyright © 2010 American Diabetes Association, reprinted with permission; and Reference 72

A national Norwegian childhood-onset (age <15 years) type 1 diabetes cohort found cause-specific mortality there to be dramatically different from that in the United States. The overall proportions of death by major cause in Norway are: acute complications (22%), CVD (15%), renal disease (8%), infection (5%), and violence or accident (28%) (47). Notably, the Norwegian cohort had smaller proportions of both CVD and infections than the U.S. cohort (15% vs. 35% and 5% vs. 16%, respectively), but larger proportions of both acute complications and violent deaths (22% vs. 16% and 28% vs. 6%, respectively) (Figure 35.13) (47,50). While a direct comparison of rates rather than proportions would be more informative, these data are unavailable and highlight the need for additional international multi-center studies (like DERI), where more direct comparisons of type 1 diabetes mortality can be made.

#### “Dead-in-Bed” Syndrome

“Dead-in-bed” syndrome refers to a small subset of deaths in young (age <50 years), otherwise healthy individuals with type 1 diabetes (i.e., no diabetic complications) who are found dead in their beds without any evidence of a struggle or sweating commonly seen with a hypoglycemic event (76). Initially described in 1991 by Tattersall and Gill (77), fewer than 200 such cases have been reported worldwide. One estimate (76) suggests that “sudden unexplained death” may be increased tenfold in type 1 diabetes, although comparable data in the general population are scarce. General risk factors may include male sex, high A1c, high insulin dose, and low BMI (76). Despite the lack of clinical evidence for a hypoglycemic event at the time of death, “dead-in-bed” syndrome is believed to be associated with nocturnal hypoglycemia, which still occurs in about 50% of individuals with type 1 diabetes (78). Long-term type 1 diabetes and elevated A1c levels lead to “hypoglycemia-associated autonomic failure” (HAAF), in which the body inadequately responds to hypoglycemia. The first evidence supporting HAAF as the cause of “dead-in-bed” syndrome is a case of a 23-year-old man with a continuous glucose monitor for recurrent hypoglycemia who was found dead in bed without signs of a hypoglycemic struggle and a glucose reading of 30 mg/dL (1.67 mmol/L) around the time of death (62).

FIGURE 35.13 Proportion of Deaths by Underlying Cause, Norway Type 1 Diabetes Cohort, 1973–2002, and Allegheny County Type 1 Diabetes Cohort, 1965–2007

* Diagnosis age <15 years

† Diagnosis age <18 years

Bar charts showing that compared to Allegheny County Registry, the Norway Type 1 Diabetes Cohort had fewer cardiovascular disease and infection deaths, but more acute complications and violent deaths.

SOURCE: References 47 and 50

### Risk Factors for Mortality

#### Socioeconomic Factors

Low socioeconomic status (SES), both at and after onset of type 1 diabetes, is associated with a number of risk factors: poor glycemic control (63,79,80), smoking (81,82), dyslipidemia (81,83), hypertension (82,84), and multiple hospitalizations (85), all of which have been associated with increased mortality risk in type 1 diabetes. In addition, all-cause mortality rates in type 1 diabetes are significantly associated with the education and income levels attained by early adulthood, an association that was weakened by adjusting for other risk factors (86). However, a larger German study found that the SES effect on mortality persisted after adjusting for known mortality risk factors (71).

#### Glycemic Control

Hyperglycemia is associated with the development and progression of microvascular complications in type 1 diabetes (87). However, its relationship with macrovascular complications and mortality remains unclear (88,89), despite DCCT/EDIC trial data showing a major benefit of glycemic control for reducing rates of CVD (90). Some studies have implicated poor glycemic control in type 1 diabetes mortality (91,92), while others have found no survival advantage for improved control (71,93). The WESDR found a 2.4-fold increased risk of all-cause mortality for the highest quartile of A1c levels compared to the lowest quartile, adjusting for other diabetes-related risk factors (25). The mortality findings from the DCCT/EDIC cohort provide the most definitive data concerning this issue. A 2015 report (70) was based on 27 years of follow-up of the original DCCT cohort of 1,441 individuals who were randomized to intensive therapy (aimed at achieving A1c close to normal) or conventional therapy for a mean of 6.2 years; in the subsequent EDIC observational study, both groups largely followed intensive therapy and had similar A1c levels by 5 years of follow-up. These data showed that the intensive therapy group experienced a lower overall mortality (hazard ratio 0.67, 95% CI 0.49–0.99), although the absolute risk difference was small (109/100,000 person-years). Nonetheless, considering that the two groups were at similar levels of glycemic control during so much of the follow-up period, these data clearly underscore another major benefit of intensive therapy and better glycemic control (Figure 35.14).

FIGURE 35.14 Cumulative Incidence of Mortality From the Date of Randomization in the DCCT (starting in 1983) to December 31, 2012 for Intensive Versus Conventional Treatment Groups (Intent-to-Treat Analysis)

DCCT, Diabetes Control and Complications Trial.

Line graph showing a lower overall mortality in the intensive therapy group, although the absolute risk difference was small.

SOURCE: Reference 70

FIGURE 35.15 Standardized Mortality Ratios in Type 1 Diabetes Compared to the General Population by Level of Albuminuria, FinnDiane Study Versus Pittsburgh Epidemiology of Diabetes Complications Study

Albuminuria status is based on urinary albumin excretion rate (AER) – normoalbuminuria: AER <20 μg/min; microalbuminuria: AER 20-200 μg/min; macroalbuminuria: AER >200 μg/min. End-stage renal disease is defined as renal failure on dialysis or transplantation. Error bars represent 95% confidence intervals. EDC, Epidemiology of Diabetes Complications Study; FinnDiane, Finnish Diabetic Nephropathy study.

* Based on 7 years of follow-up (1997–2007).

† Based on 20 years of follow-up (1986–2008).

Bar graph showing that in the absence of microalbuminuria, people with type 1 diabetes appear to have mortality rates similar to those in the general population over a 7-year period.

SOURCE: Reference 100, copyright © 2009 American Diabetes Association, reprinted with permission; and Reference 101, copyright © 2010 Springer, reprinted with permission

#### Other Cardiovascular Risk Factors

Hypertension. Studies conducted in the 1980s indicated that higher blood pressure was associated with type 1 diabetes mortality (64,94). The New Jersey 725 Study showed that hypertension was a strong independent predictor for all-cause mortality at 3 years of follow-up (29). Given the well-established relationship between hypertension and both CVD (65,89) and nephropathy (66,95,96) in type 1 diabetes, it is likely that the association between hypertension and mortality results from the impact of hypertension on these complications.

Smoking. A prospective study examining the relationship between mortality and smoking in the CHP cohort diagnosed during 1950–1964 found that heavy smoking was a significant independent predictor of all-cause mortality among females but not males (67). These data also showed an excess mortality in females that was explained by an excess risk of coronary heart disease mortality. Contemporary studies have not further examined smoking as an independent risk factor for mortality in type 1 diabetes, although smoking was not independently associated with increased mortality in the New Jersey 725 Study (29).

Renal Failure. The development of macroalbuminuria in type 1 diabetes is known to bear excess mortality risk (39). The importance of microalbuminuria per se has been less clear, due to its often transient nature and its debatable prediction of those at risk of more serious renal disease (68,69,97,98). Although renal damage (albuminuria) is a risk factor for CVD, the relationship between the two conditions remains unclear (99). Landmark findings from the Finnish Diabetic Nephropathy (FinnDiane) Study showed that in the absence of microalbuminuria, individuals with type 1 diabetes appear to have mortality rates similar to those in the general population over a 7-year period (Figure 35.15) (100). The Pittsburgh EDC Study confirmed these findings and extended them to 20 years of follow-up (Figure 35.15) (101). These intriguing findings suggest that while microalbuminuria is a strong marker for mortality risk, it is likely to reflect mechanisms beyond renal disease per se, as only a minority die in renal failure.

Dyslipidemia. While dyslipidemia has been associated with other risk factors, such as SES (81,83), it was only in 2010 that it was found to be independently associated with mortality. As with both type 2 diabetes and the general population, mortality risk in type 1 diabetes increases with higher triglyceride and low-density lipoprotein (LDL) cholesterol levels and lower high-density lipoprotein (HDL) cholesterol levels (102,103).

#### Insulin Resistance

Type 1 diabetes is less commonly associated with insulin resistance than type 2 diabetes. No data exist relating insulin resistance independently to mortality in type 1 diabetes. However, insulin resistance is a risk factor for major complications in type 1 diabetes, including nephropathy and CVD (89). In fact, insulin resistance-related factors are more strongly associated with cardiovascular outcomes than is glycemic control (89).

### United States Compared to Other Countries

Prior to the 1970s, few studies differentiated participants as having type 1 or type 2 diabetes, and fewer still used standardized methodologies to compare type 1 diabetes both nationally and internationally. A study from Cincinnati, Ohio, in 1971, was the first real attempt to standardize type 1 diabetes cohorts (diagnosed at age <17 years) and compare cumulative mortality at different clinics. At 25 years diabetes duration, cumulative mortality in Cincinnati was 20%, compared to 19% in Boston and 22% in Stockholm, Sweden (104).

During the 1980s and 1990s, DERI produced a series of type 1 diabetes mortality studies in four countries—nationwide cohorts in Finland, Israel, and Japan, as well as a U.S. cohort, represented by Allegheny County (Table 35.4) (39,40,42,48,72,105). Participants were diagnosed with diabetes between 1965 and 1979 before their 18th birthday and treated with insulin (39,105,106). These reports showed that Japan had a much higher mortality rate than the other countries, despite (or perhaps due to) having the lowest incidence of type 1 diabetes. Thus, physicians were less likely to diagnose and treat type 1 diabetes as effectively, as evidenced by Japan’s excess mortality attributable to acute complications and renal disease (39,105). Renal failure-related mortality rates in Japan were twice as high as in Allegheny County (107). Finland had an excess in number of violent deaths (often suicide) in young males, and internationally, males with type 1 diabetes tended to have higher rates of mortality than females (Table 35.5) (40,42,45,46,47,72). Looking specifically at diabetes-related deaths among individuals with type 1 diabetes, diabetes contributed to only 64% of deaths in Finland, compared to 96% in Japan, 83% in Israel, and 75% in the United States (39).

TABLE 35.4 Age-Adjusted Mortality Rates by Country in the Diabetes Epidemiology Research International Study

FOLLOW-UP THROUGH (REF.) | DEATH RATES PER 100,000 PERSON-YEARS (95% CONFIDENCE INTERVAL)
FOLLOW-UP THROUGH (REF.) | United States^*^ | Finland | Israel | Japan
1/1/1985 (39) | 238 | 171 | 159 | 681
1/1/1990 (105) | 408 | 250 | 158 | 760
12/31/1994 (42) | | 352 (315–393) | | 607 (510–718)
1/1/1999 (48) | 627 (532–728)
1/1/2008 (40) | 812 (717–907)

* Allegheny County Type 1 Diabetes Registry cohort

SOURCE: Reference 72 and references listed within the table.

TABLE 35.5 Comparison of Sex-Specific Mortality Rates in Different Type 1 Diabetes Populations

POPULATION, YEAR (REF.) | FOLLOW-UP (YEARS) | DEATHS | N | MALE/FEMALE MORTALITY RATE^*^ | MALE:FEMALE RATE RATIO
Allegheny County, Pennsylvania, 1965–2007 (40) | 30 | 202 | 1,075 | 601 / 751 | 0.80
Finland, 1965–1994 (42) | 15 | 319 | 5,126 | 448 / 238 | 1.88
Japan, 1965–1994 (42) | 15 | 137 | 1,408 | 617 / 601 | 1.03
New Zealand, 1984–2003 (45) | 20 | 115 | 430 | 29% / 24%^†^ | 1.23
United Kingdom, 1972–2000 (46) | 13 | 949 | 23,752 | 336 / 257 | 1.29
Norway, 1973–2002 (47) | 20 | 103 | 1,906 | 300 / 130 | 2.26

* Mortality rate per 100,000 person-years

† Mortality rate is calculated as the percentage of deaths in participants who were age <30 years at diagnosis during the 20-year follow-up.

SOURCE: Reference 72 and references listed within the table.

Over time, overall mortality rates in Finland and the United States continued to rise, as would be expected, with increasing age and type 1 diabetes duration, whereas Japan’s overall mortality rates decreased for type 1 diabetes, indicating dramatic improvements in type 1 diabetes care in Japan (Table 35.4) (42,72). If the United States had the same type 1 diabetes mortality rates as Finland, more than half of the type 1 diabetes deaths each year in the United States would not occur (106). A larger, more recent study using multiple registries confirmed that Japan, along with Russia and Eastern Europe, had the highest type 1 diabetes mortality rates and that mortality rates varied tenfold between countries in the World Health Organization DIAMOND Project Group (108).

## Conclusion

Despite significant advances in diabetes management and care, persons with type 1 diabetes remain at increased risk of death, though the absence of microalbuminuria appears to minimize this risk and such individuals may have a normal life expectancy. Few studies have accurately quantified modern mortality risk in large, representative samples of individuals with type 1 diabetes. The research reported herein speaks to the continuing necessity for monitoring type 1 diabetes morbidity and mortality in the United States and improving diabetes health care in the United States, where mortality is higher than in many other countries. The full effect of modern management of type 1 diabetes on mortality is still unknown; however, the long-awaited data from the DCCT/EDIC study (70) suggest reduced mortality is another benefit of intensive therapy.

## List of Abbreviations

A1c: glycosylated hemoglobin
ACR: Allegheny County Type 1 Diabetes Registry
BMI: body mass index
CHP: Children’s Hospital of Pittsburgh
CI: confidence interval
CVD: cardiovascular disease
DCCT/EDIC: Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study
DERI: Diabetes Epidemiology Research International
DKA: diabetic ketoacidosis
EDC: Epidemiology of Diabetes Complications study
ESRD: end-stage renal disease
HAAF: hypoglycemia-associated autonomic failure
SES: socioeconomic status
WESDR: Wisconsin Epidemiologic Study of Diabetic Retinopathy

## References

1 Marks HH: Longevity and mortality of diabetics. Am J Public Health Nations Health 55:416–423, 1965 14263074
2 Chute AL: Survey of patients with juvenile diabetes mellitus. Am J Dis Child 75:1–10, 1948 18903377
3 Pillow RP, Palmer LJ: Juvenile diabetes; preliminary study of 25 cases of 20 years or more duration. Northwest Med 48:101–104, 1949 18109653
4 Paz-Guevara AT, Hsu TH, White P: Juvenile diabetes mellitus after forty years. Diabetes 24:559–565, 1975 1140512
5 Entmacher PS, Root HF, Marks HH: Longevity of diabetic patients in recent years. Diabetes 13:373–377, 1964 14210681
6 Imerslund O: The prognosis in diabetes with onset before age two. Acta Paediatr 49:243–248, 1960 13852754
7 Daeschner CW, Deisher RW, Hartmann AF: Later status of juvenile diabetics. J Pediatr 38:8–17, 1951 14804247
8 Joos TH, Johnston JA: A long term evaluation of the juvenile diabetic. J Pediatr 50:133–137, 1957 13385770
9 Root HF, Barclay P: Diabetes of thirty-five years’ duration. JAMA 161:801–806, 1956
10 Marble A: Insulin—clinical aspects: the first fifty years. Diabetes 21(Suppl 2):632–636, 1972 4626568
11 Pollack AA, McGurl TJ, Macintyre N: Diabetes mellitus. A review of mortality experience. Arch Intern Med 119:161–163, 1967 6017125
12 Davidson MB: The continually changing natural history of diabetes mellitus. J Chron Dis 34:5–10, 1981 7005254
13 Goodkin G: Mortality factors in diabetes. A 20 year mortality study. J Occup Med 17:716–721, 1975 1195031
14 Hirohata T, MacMahon B, Root HF: The natural history of diabetes. I. Mortality. Diabetes 16:875–881, 1967 6081892
15 Kessler II: Mortality experience of diabetic patients. A twenty-six-year follow-up study. Am J Med 51:715–724, 1971 5129542
16 Sultz HA, Schlesinger ER, Mosher WE, Feldman JG: Long-Term Childhood Illness. Pittsburgh, PA, University of Pittsburgh Press, 1972
17 Dorman JS, LaPorte RE, Kuller LH, Cruickshanks KJ, Orchard TJ, Wagener DK, Becker DJ, Cavender DE, Drash AL: The Pittsburgh insulin-dependent diabetes mellitus (IDDM) morbidity and mortality study. Mortality results. Diabetes 33:271–276, 1984 6698317
18 LaPorte RE, Fishbein HA, Drash AL, Kuller LH, Schneider BB, Orchard TJ, Wagener DK: The Pittsburgh insulin-dependent diabetes mellitus (IDDM) registry. The incidence of insulin-dependent diabetes mellitus in Allegheny County, Pennsylvania (1965–1976). Diabetes 30:279–284, 1981 7202862
19 LaPorte RE, Orchard TJ, Kuller LH, Wagener DK, Drash AL, Schneider BB, Fishbein HA: The Pittsburgh Insulin Dependent Diabetes Mellitus Registry: the relationship of insulin dependent diabetes mellitus incidence to social class. Am J Epidemiol 114:379–384, 1981 7304573
20 Dorman JS, Tajima N, LaPorte RE, Becker DJ, Cruickshanks KJ, Wagener DK, Orchard TJ, Drash AL: The Pittsburgh Insulin-Dependent Diabetes Mellitus (IDDM) Morbidity and Mortality Study: case-control analyses of risk factors for mortality. Diabetes Care 8(Suppl 1):54–60, 1985 4053954
21 LaPorte RE, Tajima N, Dorman JS, Cruickshanks KJ, Eberhardt MS, Rabin BS, Atchison RW, Wagener DK, Becker DJ, Orchard TJ, Songer TJ, Slemenda CW, Kuller LH, Drash AL: Differences between blacks and whites in the epidemiology of insulin-dependent diabetes mellitus in Allegheny County, Pennsylvania. Am J Epidemiol 123:592–603, 1986 3456700
22 Pambianco G, Costacou T, Ellis D, Becker DJ, Klein R, Orchard TJ: The 30-year natural history of type 1 diabetes complications: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes 55:1463–1469, 2006 16644706
23 Klein R, Klein BE, Moss SE, DeMets DL, Kaufman I, Voss PS: Prevalence of diabetes mellitus in southern Wisconsin. Am J Epidemiol 119:54–61, 1984 6691336
24 Klein BE, Klein R, McBride PE, Cruickshanks KJ, Palta M, Knudtson MD, Moss SE, Reinke JO: Cardiovascular disease, mortality, and retinal microvascular characteristics in type 1 diabetes: Wisconsin epidemiologic study of diabetic retinopathy. Arch Intern Med 164:1917–1924, 2004 15451768
25 Shankar A, Klein R, Klein BE, Moss SE: Association between glycosylated hemoglobin level and cardiovascular and all-cause mortality in type 1 diabetes. Am J Epidemiol 166:393–402, 2007 17526864
26 Goebel-Fabbri AE, Fikkan J, Franko DL, Pearson K, Anderson BJ, Weinger K: Insulin restriction and associated morbidity and mortality in women with type 1 diabetes. Diabetes Care 31:415–419, 2008 18070998
27 Nielsen S, Emborg C, Molbak AG: Mortality in concurrent type 1 diabetes and anorexia nervosa. Diabetes Care 25:309–312, 2002 11815501
28 Walker JD, Young RJ, Little J, Steel JM: Mortality in concurrent type 1 diabetes and anorexia nervosa. Diabetes Care 25:1664–1665, 2002
29 Roy M, Rendas-Baum R, Skurnick J: Mortality in African-Americans with type 1 diabetes: The New Jersey 725. Diabet Med 23:698–706, 2006 16759315
30 Dabelea D, Bell RA, D’Agostino RB, Jr., Imperatore G, Johansen JM, Linder B, Liu LL, Loots B, Marcovina S, Mayer-Davis EJ, Pettitt DJ, Waitzfelder B; Writing Group for the SEARCH for Diabetes in Youth Study Group: Incidence of diabetes in youth in the United States. JAMA 297:2716–2724, 2007 17595272
31 Centers for Disease Control and Prevention: Diabetes death rates among youths aged ≤ 19 years—United States, 1968–2009. MMWR Morb Mortal Wkly Rep 61:869–872, 2012 23114253
32 Green A, Borch-Johnsen K, Andersen PK, Hougaard P, Keiding N, Kreiner S, Deckert T: Relative mortality of type 1 (insulin-dependent) diabetes in Denmark: 1933–1981. Diabetologia 28:339–342, 1985 4043578
33 Borch-Johnsen K, Kreiner S, Deckert T: Mortality of type 1 (insulin-dependent) diabetes mellitus in Denmark: a study of relative mortality in 2930 Danish type 1 diabetic patients diagnosed from 1933 to 1972. Diabetologia 29:767–772, 1986 3493184
34 Borch-Johnsen K: Improving prognosis of type 1 diabetes. Mortality, accidents, and impact on insurance. Diabetes Care 22(Suppl 2):B1–3, 1999
35 Narayan KM, Boyle JP, Thompson TJ, Sorensen SW, Williamson DF: Lifetime risk for diabetes mellitus in the United States. JAMA 290:1884–1890, 2003 14532317
36 Miller RG, Secrest AM, Sharma RK, Songer TJ, Orchard TJ: Improvements in the life expectancy of type 1 diabetes: the Pittsburgh Epidemiology of Diabetes Complications study cohort. Diabetes 61:2987–2992, 2012 22851572
37 Vander Zwaag R, Runyan JW, Jr., Davidson JK, Delcher HK, Mainzer I, Baggett HW: A cohort study of mortality in two clinic populations of patients with diabetes mellitus. Diabetes Care 6:341–346, 1983 6617410
38 Moss SE, Klein R, Klein BE: Cause-specific mortality in a population-based study of diabetes. Am J Public Health 81:1158–1162, 1991 1951827
39 International evaluation of cause-specific mortality and IDDM. Diabetes Epidemiology Research International Mortality Study Group. Diabetes Care 14:55–60, 1991 1991436
40 Secrest AM, Becker DJ, Kelsey SF, Laporte RE, Orchard TJ: All-cause mortality trends in a large population-based cohort with long-standing childhood-onset type 1 diabetes: the Allegheny County type 1 diabetes registry. Diabetes Care 33:2573–2579, 2010 21115767
41 Kostraba JN, Dorman JS, LaPorte RE, Kuller LH, Orchard TJ, Becker DJ, Drash AL: The investigation of age at onset as a risk factor for mortality in persons with insulin-dependent diabetes mellitus using Cox proportional hazards models. Am J Epidemiol 133:67–72, 1991 1983900
42 Asao K, Sarti C, Forsen T, Hyttinen V, Nishimura R, Matsushima M, Reunanen A, Tuomilehto J, Tajima N; Diabetes Epidemiology Research International Mortality Study Group: Long-term mortality in nationwide cohorts of childhood-onset type 1 diabetes in Japan and Finland. Diabetes Care 26:2037–2042, 2003 12832309
43 Knowles HC, Jr., Guest GM, Lampe J, Kessler M, Skillman TG: The course of juvenile diabetes treated with unmeasured diet. Diabetes 14:239–273, 1965 14280367
44 Kostraba JN, Dorman JS, Orchard TJ, Becker DJ, Ohki Y, Ellis D, Doft BH, Lobes LA, LaPorte RE, Drash AL: Contribution of diabetes duration before puberty to development of microvascular complications in IDDM subjects. Diabetes Care 12:686–693, 1989 2612303
45 Dawson SI, Willis J, Florkowski CM, Scott RS: All-cause mortality in insulin-treated diabetic patients: a 20-year follow-up. Diabetes Res Clin Pract 80:e6–9, 2008 18329123
46 Laing SP, Swerdlow AJ, Slater SD, Burden AC, Morris A, Waugh NR, Gatling W, Bingley PJ, Patterson CC: Mortality from heart disease in a cohort of 23,000 patients with insulin-treated diabetes. Diabetologia 46:760–765, 2003 12774166
47 Skrivarhaug T, Bangstad HJ, Stene LC, Sandvik L, Hanssen KF, Joner G: Long-term mortality in a nationwide cohort of childhood-onset type 1 diabetic patients in Norway. Diabetologia 49:298–305, 2006 16365724
48 Nishimura R, LaPorte RE, Dorman JS, Tajima N, Becker D, Orchard TJ: Mortality trends in type 1 diabetes. The Allegheny County (Pennsylvania) Registry 1965–1999. Diabetes Care 24:823–827, 2001 11347737
49 Sex differences in the mortality associated with insulin-dependent diabetes mellitus in four countries. The Diabetes Epidemiology Research International (DERI) Study. Am J Epidemiol 133:577–584, 1991 2006644
50 Secrest AM, Becker DJ, Kelsey SF, Laporte RE, Orchard TJ: Cause-specific mortality trends in a large population-based cohort with long-standing childhood-onset type 1 diabetes. Diabetes 59:3216–3222, 2010 20739685
51 Dahlquist G, Kallen B: Mortality in childhood-onset type 1 diabetes: a population-based study. Diabetes Care 28:2384–2387, 2005 16186267
52 Patterson CC, Dahlquist G, Harjutsalo V, Joner G, Feltbower RG, Svensson J, Schober E, Gyurus E, Castell C, Urbonaite B, Rosenbauer J, Iotova V, Thorsson AV, Soltesz G: Early mortality in EURODIAB population-based cohorts of type 1 diabetes diagnosed in childhood since 1989. Diabetologia 50:2439–2442, 2007 17901942
53 Tull ES, Barinas E: A twofold excess mortality among black compared with white IDDM patients in Allegheny County, Pennsylvania. Pittsburgh DERI Mortality Study Group. Diabetes Care 19:1344–1347, 1996 8941461
54 Bosnyak Z, Nishimura R, Hagan Hughes M, Tajima N, Becker D, Tuomilehto J, Orchard TJ: Excess mortality in Black compared with White patients with type 1 diabetes: an examination of underlying causes. Diabet Med 22:1636–1641, 2005 16401305
55 Burnet DL, Cooper AJ, Drum ML, Lipton RB: Risk factors for mortality in a diverse cohort of patients with childhood-onset diabetes in Chicago. Diabetes Care 30:2559–2563, 2007 17644621
56 Lipton R, Good G, Mikhailov T, Freels S, Donoghue E: Ethnic differences in mortality from insulin-dependent diabetes mellitus among people less than 25 years of age. Pediatrics 103(5 Pt 1):952–956, 1999 10224171
57 Washington RE, Orchard TJ, Arena VC, Laporte RE, Secrest AM, Tull ES: All-cause mortality in a population-based type 1 diabetes cohort in the U.S. Virgin Islands. Diabetes Res Clin Pract 103:504–509, 2014 24439208
58 Murray CJ, Kulkarni S, Ezzati M: Eight Americas: new perspectives on U.S. health disparities. Am J Prev Med 29(5 Suppl 1)):4–10, 2005 16389119
59 de Faire U, Friberg L, Lorich U, Lundman T: A validation of cause-of-death certification in 1,156 deaths. Acta Med Scand 200:223–228, 1976 970229
60 Messite J, Stellman SD: Accuracy of death certificate completion: the need for formalized physician training. JAMA 275:794–796, 1996 8598597
61 Muhlhauser I, Sawicki PT, Blank M, Overmann H, Richter B, Berger M: Reliability of causes of death in persons with type I diabetes. Diabetologia 45:1490–1497, 2002 12436331
62 Tanenberg RJ, Newton CA, Drake AJ: Confirmation of hypoglycemia in the “dead-in-bed” syndrome as captured by a retrospective continuous glucose monitoring system. Endocr Pract 16:244–248, 2010 19833577
63 Hassan K, Loar R, Anderson BJ, Heptulla RA: The role of socioeconomic status, depression, quality of life, and glycemic control in type 1 diabetes mellitus. J Pediatr 149:526–531, 2006 17011326
64 Christlieb AR, Warram JH, Krolewski AS, Busick EJ, Ganda OP, Asmal AC, Soeldner JS, Bradley RF: Hypertension: the major risk factor in juvenile-onset insulin-dependent diabetics. Diabetes 30(Suppl 2):90–96, 1981 7297776
65 Roy MS, Peng B, Roy A: Risk factors for coronary disease and stroke in previously hospitalized African-Americans with type 1 diabetes: a 6-year follow-up. Diabet Med 24:1361–1368, 2007 17976202
66 Predictors of the development of microalbuminuria in patients with type 1 diabetes mellitus: a seven-year prospective study. The Microalbuminuria Collaborative Study Group. Diabet Med 16:918–925, 1999 10588521
67 Moy CS, LaPorte RE, Dorman JS, Songer TJ, Orchard TJ, Kuller LH, Becker DJ, Drash AL: Insulin-dependent diabetes mellitus mortality. The risk of cigarette smoking. Circulation 82:37–43, 1990 2364522
68 Retnakaran R, Cull CA, Thorne KI, Adler AI, Holman RR; UKPDS Study Group: Risk factors for renal dysfunction in type 2 diabetes: U.K. Prospective Diabetes Study 74. Diabetes 55:1832–1839, 2006 16731850
69 Kramer HJ, Nguyen QD, Curhan G, Hsu CY: Renal insufficiency in the absence of albuminuria and retinopathy among adults with type 2 diabetes mellitus. JAMA 289:3273–3277, 2003 12824208
70 Orchard TJ, Nathan DM, Zinman B, Cleary P, Brillon D, Backlund JY, Lachin JM; Writing Group for the DCCT/EDIC Research Group: Association between 7 years of intensive treatment of type 1 diabetes and long-term mortality. JAMA 313:45–53, 2015 25562265
71 Muhlhauser I, Overmann H, Bender R, Jorgens V, Berger M: Predictors of mortality and end-stage diabetic complications in patients with type 1 diabetes mellitus on intensified insulin therapy. Diabet Med 17:727–734, 2000 11110506
72 Secrest AM. Mortality trends in a population-based type 1 diabetes cohort. Dissertation, University of Pittsburgh. Ann Arbor, MI: ProQuest/UMI, 2010. Publication No. AAT 3435523
73 Scibilia J, Finegold D, Dorman J, Becker D, Drash A: Why do children with diabetes die? Acta Endocrinol Suppl (Copenh) 279:326–333, 1986 3096039
74 Laing SP, Swerdlow AJ, Slater SD, Botha JL, Burden AC, Waugh NR, Smith AW, Hill RD, Bingley PJ, Patterson CC, Qiao Z, Keen H: The British Diabetic Association Cohort Study, I: all-cause mortality in patients with insulin-treated diabetes mellitus. Diabet Med 16:459–465, 1999 10391392
75 Borch-Johnsen K, Nissen H, Henriksen E, Kreiner S, Salling N, Deckert T, Nerup J: The natural history of insulin-dependent diabetes mellitus in Denmark: 1. Long-term survival with and without late diabetic complications. Diabet Med 4:201–210, 1987 2956020
76 Secrest AM, Becker DJ, Kelsey SF, Laporte RE, Orchard TJ: Characterizing sudden death and dead-in-bed syndrome in type 1 diabetes: analysis from two childhood-onset type 1 diabetes registries. Diabet Med 28:293–300, 2011 21309837
77 Tattersall RB, Gill GV: Unexplained deaths of type 1 diabetic patients. Diabet Med 8:49–58, 1991 1826245
78 Woodward A, Weston P, Casson IF, Gill GV: Nocturnal hypoglycaemia in type 1 diabetes—frequency and predictive factors. QJM 102:603–607, 2009 19574471
79 Ismail IS, Nazaimoon WM, Mohamad WB, Letchuman R, Singaraveloo M, Pendek R, Faridah I, Rasat R, Sheriff IH, Khalid BA: Sociodemographic determinants of glycaemic control in young diabetic patients in peninsular Malaysia. Diabetes Res Clin Pract 47:57–69, 2000 10660222
80 Araujo MB, Mazza CS: Assessment of risk factors of poor metabolic control in type 1 diabetic children assisted in a public hospital in Argentina. Pediatr Diabetes 9:480–487, 2008 18761645
81 Unwin N, Binns D, Elliott K, Kelly WF: The relationships between cardiovascular risk factors and socio-economic status in people with diabetes. Diabet Med 13:72–79, 1996 8741816
82 Nadas J, Putz Z, Fovenyi J, Gaal Z, Gyimesi A, Hidvegi T, Hosszufalusi N, Neuwirth G, Oroszlan T, Panczel P, Vandorfi G, Winkler G, Wittmann I, Jermendy G: Cardiometabolic risk and educational level in adult patients with type 1 diabetes. Acta Diabetol 46:159–162, 2009 18843447
83 Robinson N, Edouard L, Diehl A, Fuller JH: Social class and risk factors for vascular disease in diabetes. Diabetes Metab 10:245–249, 1984
84 Chaturvedi N, Jarrett J, Shipley MJ, Fuller JH: Socioeconomic gradient in morbidity and mortality in people with diabetes: cohort study findings from the Whitehall Study and the WHO Multinational Study of Vascular Disease in Diabetes. BMJ 316:100–105, 1998 9462313
85 Kovacs M, Charron-Prochownik D, Obrosky DS: A longitudinal study of biomedical and psychosocial predictors of multiple hospitalizations among young people with insulin-dependent diabetes mellitus. Diabet Med 12:142–148, 1995 7743761
86 Secrest AM, Costacou T, Gutelius B, Miller RG, Songer TJ, Orchard TJ: Association of socioeconomic status with mortality in type 1 diabetes: the Pittsburgh epidemiology of diabetes complications study. Ann Epidemiol 21:367–373, 2011 21458730
87 The effect of intensive treatment of diabetes on the development and progression of long-term complications in insulin-dependent diabetes mellitus. The Diabetes Control and Complications Trial Research Group. N Engl J Med 329:977–986, 1993 8366922
88 Orchard TJ, Costacou T, Kretowski A, Nesto RW: Type 1 diabetes and coronary artery disease. Diabetes Care 29:2528–2538, 2006 17065698
89 Orchard TJ, Olson JC, Erbey JR, Williams K, Forrest KY, Smithline Kinder L, Ellis D, Becker DJ: Insulin resistance-related factors, but not glycemia, predict coronary artery disease in type 1 diabetes: 10-year follow-up data from the Pittsburgh Epidemiology of Diabetes Complications Study. Diabetes Care 26:1374–1379, 2003 12716791
90 Lachin JM, Orchard TJ, Nathan DM; DCCT/EDIC Research Group: Update on cardiovascular outcomes at 30 years of the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study. Diabetes Care 37:39–43, 2014 24356596
91 Lehto S, Ronnemaa T, Pyorala K, Laakso M: Poor glycemic control predicts coronary heart disease events in patients with type 1 diabetes without nephropathy. Arterioscler Thromb Vasc Biol 19:1014–1019, 1999 10195930
92 Moss SE, Klein R, Klein BE, Meuer SM: The association of glycemia and cause-specific mortality in a diabetic population. Arch Intern Med 154:2473–2479, 1994 7979844
93 Weis U, Turner B, Gibney J, Watts GF, Burke V, Shaw KM, Cummings MH: Long-term predictors of coronary artery disease and mortality in type 1 diabetes. QJM 94:623–630, 2001 11704692
94 Klein R, Moss SE, Klein BE, DeMets DL: Relation of ocular and systemic factors to survival in diabetes. Arch Intern Med 149:266–272, 1989 2916872
95 Yishak AA, Costacou T, Virella G, Zgibor J, Fried L, Walsh M, Evans RW, Lopes-Virella M, Kagan VE, Otvos J, Orchard TJ: Novel predictors of overt nephropathy in subjects with type 1 diabetes. A nested case control study from the Pittsburgh Epidemiology of Diabetes Complications cohort. Nephrol Dial Transplant 21:93–100, 2006 16144851
96 Roy MS, Affouf M, Roy A: Six-year incidence of proteinuria in type 1 diabetic African Americans. Diabetes Care 30:1807–1812, 2007 17475942
97 Molitch ME, Steffes M, Sun W, Rutledge B, Cleary P, de Boer IH, Zinman B, Lachin J; Epidemiology of Diabetes Interventions and Complications Study Group: The development and progression of renal insufficiency with and without albuminuria in adults with type 1 diabetes mellitus in the Diabetes Control and Complications Trial and Epidemiology of Diabetes Interventions and Complications Study. Diabetes Care 33:1536–1543, 2010 20413518
98 de Boer IH, Sun W, Cleary PA, Lachin JM, Molitch ME, Steffes MW, Zinman B; DCCT/EDIC Research Group: Intensive diabetes therapy and glomerular filtration rate in type 1 diabetes. N Engl J Med 365:2366–2376, 2011 22077236
99 Pambianco G, Costacou T, Orchard TJ: The prediction of major outcomes of type 1 diabetes: a 12-year prospective evaluation of three separate definitions of the metabolic syndrome and their components and estimated glucose disposal rate: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes Care 30:1248–1254, 2007 17303788
100 Groop PH, Thomas MC, Moran JL, Waden J, Thorn LM, Makinen VP, Rosengard-Barlund M, Saraheimo M, Hietala K, Heikkila O, Forsblom C; FinnDiane Study Group: The presence and severity of chronic kidney disease predicts all-cause mortality in type 1 diabetes. Diabetes 58:1651–1658, 2009 19401416
101 Orchard TJ, Secrest AM, Miller RG, Costacou T: In the absence of renal disease, 20 year mortality risk in type 1 diabetes is comparable to that of the general population: a report from the Pittsburgh Epidemiology of Diabetes Complications Study. Diabetologia 53:2312–2319, 2010 20665208
102 Grauslund J, Jorgensen TM, Nybo M, Green A, Rasmussen LM, Sjolie AK: Risk factors for mortality and ischemic heart disease in patients with long-term type 1 diabetes. J Diabetes Complications 24:223–228, 2010 19577486
103 Makinen VP, Soininen P, Kangas AJ, Forsblom C, Tolonen N, Thorn LM, Viikari J, Raitakari OT, Savolainen M, Groop PH, Ala-Korpela M; Finnish Diabetic Nephropathy Study Group: Triglyceridecholesterol imbalance across lipoprotein subclasses predicts diabetic kidney disease and mortality in type 1 diabetes: the FinnDiane Study. J Intern Med 273:383–395, 2013 23279644
104 Knowles HC: Long-term juvenile diabetes treated with unmeasured diet. Transactions Assoc Amer Phys 34:95–101, 1971
105 Major cross-country differences in risk of dying for people with IDDM. Diabetes Epidemiology Research International Mortality Study Group. Diabetes Care 14:49–54, 1991 1991435
106 International analysis of insulin-dependent diabetes mellitus mortality: a preventable mortality perspective. The Diabetes Epidemiology Research International (DERI) Study. Am J Epidemiol 142:612–618, 1995 7653470
107 Matsushima M, Tajima N, LaPorte RE, Orchard TJ, Tull ES, Gower IF, Kitagawa T: Markedly increased renal disease mortality and incidence of renal replacement therapy among IDDM patients in Japan in contrast to Allegheny County, Pennsylvania, USA. Diabetes Epidemiology Research International (DERI) U.S.-Japan Mortality Study Group. Diabetologia 38:236–243, 1995 7713320
108 Matsushima M, LaPorte RE, Maruyama M, Shimizu K, Nishimura R, Tajima N: Geographic variation in mortality among individuals with youth-onset diabetes mellitus across the world. DERI Mortality Study Group. Diabetes Epidemiology Research International. Diabetologia 40:212–216, 1997 9049483