# CHAPTER 25 Impact of Sleep and Circadian Disturbances on Glucose Metabolism and Type 2 Diabetes

## Summary

The term “sleep disturbance” is widely used to refer to a variety of conditions, including sleep insufficiency, sleep fragmentation, sleep disorders, such as sleep apnea, and misaligned sleep, as occurs in shift workers. Insufficient sleep and sleep fragmentation are linked to abnormal glucose metabolism, insulin sensitivity reduction of 20%–30%, and increased diabetes risk. Well-controlled laboratory studies have provided insights regarding the underlying mechanisms. Multiple large prospective studies have found that that these sleep disturbances increase the risk of incident diabetes by as much as 30%–50%. Obstructive sleep apnea (OSA), which combines sleep fragmentation and hypoxemia, has been identified as a risk factor for insulin resistance and diabetes. OSA is highly prevalent in patients with type 2 diabetes, affecting roughly two out of three patients, and its severity correlates with glycemic control. Whether glycemic control can be improved by treating OSA remains controversial. Sleep disturbances during pregnancy are linked to gestational diabetes and hyperglycemia, and there is evidence for potential adverse effects on maternal and fetal health. Evidence from animal models has identified disruption of the circadian system as a putative risk factor for adverse metabolic outcomes. Shift work, a condition of chronic circadian disruption, is linked to weight gain and incident obesity and diabetes.

As sleep disturbances are increasingly common in modern society and may play a role in the epidemic of type 2 diabetes, strategies to prevent diabetes or reduce its severity should consider optimizing sleep health in at-risk populations. Intervention studies demonstrating that treating sleep disturbances may help prevent diabetes or improve glycemic control are lacking but have become an area of intense research.

## Introduction

Humans spend approximately one-third of their lifetime sleeping. Sleep is viewed as a state of energy conservation and replenishment of energy stores. Normal human sleep is composed of rapid-eye-movement (REM) sleep and stages N1, N2, and N3 of non-REM (NREM) sleep. N3 is the deepest stage of NREM sleep and is also known as slow wave sleep (SWS). Oscillations between REM and NREM stages occur roughly every 90 minutes and repeat four to six times throughout the night.

This important physiologic process is controlled in part by an internal circadian clock and in part by a homeostatic mechanism where the pressure for sleep increases in proportion to the duration of prior wakefulness. Human behavior may override these physiologic control mechanisms, resulting in alterations of sleep duration, quality, or timing. Increasing prevalence of sleep disorders, such as obstructive sleep apnea (OSA), parallels the increase in obesity rates. According to the definition proposed by the National Heart, Lung, and Blood Institute, “sleep deficiency” occurs when an individual has insufficient sleep, poor sleep, a diagnosed sleep disorder, or abnormal timing of sleep (1). Multiple reviews (2,3,4) have elected to use the term “sleep disturbances” to designate insufficient or excessive sleep duration, poor self-reported sleep quality, or a diagnosed sleep disorder, such as OSA. Experimental and epidemiologic data have linked insufficient sleep duration, abnormal sleep timing, and poor sleep quality to insulin resistance, increased risk of obesity, and diabetes. In patients with type 2 diabetes, sleep disturbances may adversely affect glycemic control.

OSA is well recognized as a risk factor for insulin resistance, independent of the degree of obesity, and is highly prevalent in patients with type 2 diabetes. OSA is a complex disorder involving intermittent hypoxia, sleep fragmentation, low amounts of SWS, and reduced total sleep time. Well-documented studies in animal models indicate that intermittent hypoxia is one of the mechanisms linking OSA to abnormal glucose metabolism. Whether treatment of OSA with continuous positive airway pressure (CPAP) may improve glucose metabolism remains controversial.

Pregnant women are a special population that may be particularly vulnerable to adverse effects of abnormal sleep. Sleep disturbances in pregnancy are associated with adverse maternal and fetal outcomes, including gestational diabetes, preeclampsia, and premature delivery. Because of these potential complications, the body of literature on this topic has grown rapidly.

Besides sleep duration, sleep quality, and OSA, emerging evidence from well-controlled clinical research studies has revealed that conditions where the behavioral sleep/wake cycle is not in synchrony with the biological circadian timing system, so-called “circadian misalignment,” may result in impaired glucose tolerance (IGT). In cross-sectional analyses, circadian misalignment is associated with increased diabetes risk in nondiabetic individuals and with poor glycemic control in patients with established type 2 diabetes.

This chapter summarizes the evidence linking different types of sleep disturbances to abnormal glucose metabolism, including insufficient sleep, sleep fragmentation, OSA, and circadian misalignment. Potential underlying mechanisms are discussed, as well as findings from prospective and cross-sectional epidemiologic studies and from intervention studies.

## Insufficient Sleep

While it is important to note that the amount of sleep that optimizes physical and mental health is an individual characteristic that tends to decrease with age, it is generally considered that 7–8 hours of sleep nightly is adequate for most adults (5). Partly due to changes in work and social demands, sleep duration in the United States has been declining (6). In data from 110,441 adults participating in the National Health Interview Surveys 2004–2007, the prevalences of self-reported short sleep duration were 7.8% for sleeping ≤5 hours and 20.5% for sleeping 6 hours per day (7). In 2009, >30% of U.S. men and women age 30–65 years reported sleeping <6 hours per night on workdays (6).

Insufficient sleep has been linked to reduced insulin sensitivity and increased risk of type 2 diabetes, both in laboratory studies in healthy humans and in epidemiologic studies. A causative role of partial sleep restriction in promoting alterations in glucose metabolism was first established in 1999 (8). Intravenous glucose tolerance testing (IVGTT) following sleep restriction to 4 hours per night for five nights resulted in a 24% decrease in insulin sensitivity (Figure 25.1), as well as a 30% decrease in the acute insulin response to intravenous glucose (8,9). Moreover, an increase in the HOMA (homeostatic model assessment, an index of insulin resistance) response to breakfast was observed on the following day and occurred despite similar insulin secretory responses. These findings indicated that a state of sleep debt caused a decrease in insulin sensitivity that was not compensated by increased insulin release, leading to a more than 40% decrease in glucose tolerance compared to the fully rested condition.

FIGURE 25.1 Reduction in Insulin Sensitivity as Assessed by Intravenous Glucose Tolerance Test From Laboratory Studies Involving Sleep Restriction, Sleep Fragmentation, and Intermittent Hypoxia

h, hour; SWS, slow wave sleep.

Bar graph showing insulin sensitivity reduced 16 to 32% after sleep restriction or sleep fragmentation and 58% after both sleep restriction and circadian misalignment

SOURCE: References 8, 10, 11, 12, 13, 41, and 42, as indicated in parentheses within the figure.

Several subsequent, well-controlled experimental studies in healthy human subjects involving sleep restriction to 4–5.5 hours per night for 5–14 nights and assessments of glucose metabolism by IVGTT or euglycemic-hyperinsulinemic clamp have confirmed a reduction of insulin sensitivity ranging from 16% to 32% in response to sleep restriction without simultaneous increases in insulin levels, resulting in reduced glucose tolerance and an increased risk of diabetes (Figure 25.1) (10,11,12,13). A few studies that included assessments after sleep recovery found that the metabolic disturbances induced by sleep restriction were at least partially reversible (improved glucose tolerance as assessed by IVGTT (8) and a reduction in the insulin-to-glucose ratio (14)).

Further, 2 weeks of sleep extension in habitual short sleepers resulted in changes in indices of fasting insulin sensitivity that were correlated with the amount of sleep extension, with those obtaining more sleep having the largest increases in insulin sensitivity (15). Lastly, a small study indicated that three nights of in-laboratory “catch-up” sleep in men with chronic, repetitive, lifestyle-driven sleep restriction led to improved insulin sensitivity as assessed by a 2-hour frequently sampled glucose tolerance test (16).

Multiple cross-sectional epidemiologic studies have indicated that self-reported short sleep duration (usually <6 hours per night) is associated with increased odds of prediabetes and diabetes. Relevant population-based studies examining associations between these conditions of abnormal glucose tolerance and self-reported short sleep duration in the United States and Canada are listed in Tables 25.1 and 25.2. Importantly, 12 of 16 large prospective studies with a follow-up duration of 2–32 years have observed that short sleep duration is associated with an increased risk of incident diabetes (Table 25.3) (17,18,19,20,21,22,23,24,25,26,27,28,29,30,31,32). All five studies conducted in the United States, including the Nurses’ Health Study (17), National Health and Nutrition Examination Survey (NHANES) I (20), NIH-AARP Diet and Health Study (24), Massachusetts Male Aging Study (25), and Millennium Cohort by the Department of Defense (28), have found the associations. A meta-analysis including 11 of these 16 studies (total 447,124 participants) concluded that short sleep (≤5–6 hours per night) predicts the development of type 2 diabetes with a relative risk (RR) of 1.33 (95% confidence interval [CI] 1.20–1.48) (21). In addition, multiple studies, the majority of which were conducted in the United States, have found that long sleep duration (>8–9 hours per night) also predicts incident diabetes (Table 25.3) (17,20,22,24,25,30), with a meta-analysis indicating a pooled relative risk of 1.48 (33). This suggests a U-shaped relationship between sleep duration and risk of incident diabetes. The main limitation of these studies is that sleep duration was self-reported.

Only a few studies have examined the impact of insufficient sleep on glycemic control in patients with established type 2 diabetes. A questionnaire survey study of 161 African Americans with type 2 diabetes found that 3 hours of perceived sleep debt per day (i.e., a self-report of insufficient sleep duration) predicted a glycosylated hemoglobin (A1c) level of 1.1% above the median (34). The magnitude of this difference is comparable to the effect size of several U.S. Food and Drug Administration-approved diabetes medications. A U-shaped relationship may exist between sleep duration and glycemic control, with excessive sleep duration predicting poorer glycemic control. A large cross-sectional study of 4,870 Japanese participants revealed higher A1c levels in patients with self-reported sleep duration <5.5 hours per night and ≥8.5 hours per night compared to those with 6.5–7.4 hours per night (35). A study using data from the Korean National Health and Nutrition Examination Survey found a U-shaped relationship between sleep duration and fasting glucose and A1c values (36), while another study of 18,121 participants in China found that only long sleep (>9 hours) was significantly associated with poorer glycemic control (37). These findings from large studies based on self-reported sleep duration were not confirmed in the limited number of studies where sleep was measured using an objective method, such as actigraphy. Indeed, in these studies (total 91 participants), sleep duration was not found to be correlated with glycemic control in patients with type 2 diabetes (38,39). This contradiction between self-reported and objectively measured sleep duration on glycemic control could be due to a very small number of participants in the latter studies, and more research is needed to confirm the findings. Taken together, the epidemiologic evidence suggests a role of self-reported sleep duration on glycemic control in type 2 diabetes.

TABLE 25.1 Studies Exploring the Relationship Between Self-Reported Sleep Duration and Dysglycemia

STUDY, YEARS (REF.) | POPULATION | SAMPLE SIZE | STUDY DESIGN | OUTCOME | RESULTS
NHANES, 2005–2006, 2007–2008 (44) | Age ≥30 years | 2,285 | Cross-sectional | Clinically identified prediabetes, defined as FPG 100–125 mg/dL, plus physician diagnosis of prediabetes | Sleeping ≤5 h/night was associated with clinically identified prediabetes, OR 2.06 (95% CI 1.00–4.22), compared to sleeping 7 h/night.; Sleeping ≥9 h/night was not associated with prediabetes.
Sleep Heart Health Study, 1995–1998 (374) | Mean age 70.2 years | 1,486 | Cross-sectional | IGT, defined as 2-hour glucose value 140–199 mg/dL, post 75 g glucose load | Sleeping ≤5 h/night was not associated with IGT.; Sleeping 6 h/night was associated with IGT, OR 1.58 (95% CI 1.15–2.18).; Sleeping ≥9 h/night was associated with IGT, OR 1.88 (95% CI 1.21–2.91).
Western New York Health Study, 1996–2004 (375) | Age 35–79 years | 1,455 (91 cases; 272 controls) | Nested case-control within a 6-year longitudinal cohort | IFG at a follow-up examination, defined as FPG 100–125 mg/dL | Sleeping <6 h/night was associated with development of IFG, OR 3.0 (95% CI 1.05–8.59).; Sleeping >8 h/night was not associated with IFG.
Quebec Family Study, 1989–2001 (30) | French Canadians from Quebec area, age 21–64 years | 276 | Longitudinal 6-year follow-up | Type 2 diabetes, defined as FPG ≥126 mg/dL or 2-hour glucose ≥200 mg/dL, post 75 g glucose challenge; IGT, defined as 2-hour glucose value 140–199 mg/dL, post 75 g glucose load | Sleeping ≤6 h/night was associated with type 2 diabetes/IGT, OR 2.78 (95% CI 1.61–4.12).; Sleeping ≥9 h/night was associated with type 2 diabetes/IGT, OR 2.54 (95% CI 1.42–3.53).

Conversions for glucose values are provided in Diabetes in America Appendix 1 Conversions. CI, confidence interval; FPG, fasting plasma glucose; h, hour; IFG, impaired fasting glucose; IGT, impaired glucose tolerance; NHANES, National Health and Nutrition Examination Survey; OR, odds ratio.

SOURCE: References are listed within the table.

TABLE 25.2 Cross-Sectional Studies Exploring Associations Between Self-Reported Sleep Duration and Diabetes

STUDY, YEARS (REF.) | POPULATION | SAMPLE SIZE | OUTCOME | RESULTS
National Sleep in America Survey, 2003 (46) | Age 55–84 years | 1,506 | Self-reported diabetes | Sleeping <6 h/night was not associated with diabetes.
National Health Interview Survey-Sample Adult Files (NHIS-SAF), 2004–2007 (7) | Age ≥18 years; mean age 46 years | 110,441 | Self-reported diabetes | Compared to sleeping 7 h, sleeping ≤5 h and 6 h were associated with diabetes, OR 1.19 (95% CI 1.07–1.33) and OR 1.09 (95% CI 1.01–1.19), respectively.; Sleeping 8 h and ≥9 h were associated with diabetes, OR 1.12 (95% CI 1.03–1.20) and OR 1.25 (95% CI 1.13–1.38), respectively.
NHANES, 2007–2008 (376) | Mean age 49.3 years | 5,649 | Self-reported diabetes | Sleeping <5 h/night was associated with self-reported diabetes, OR 1.76 (95% CI 1.13–2.74).; Sleeping ≥9 h/night was not associated with self-reported diabetes.
National Health Interview Survey, 2004–2011 (377) | Mean age 50.6 years | 130,943 (13% non-Hispanic black) | Self-reported diabetes | In non-Hispanic whites, sleeping <7 h/night and >7 h/night were associated with diabetes, PR 1.49 (95% CI 1.40–1.58) and PR 1.32 (95% CI 1.25–1.40), respectively.; In non-Hispanic blacks, corresponding PRs were 1.21 (95% CI 1.09–1.34) and 1.11 (95% CI 1.00–1.23), respectively.; Racial/ethnic differences in short sleep-diabetes association were nonsignificant after adjusting for socioeconomic status.
Behavioral Risk Factor Surveillance System, 2010 (378) | 14 U.S. states, age ≥45 years | 54,269 | Self-reported diabetes | Sleeping ≤6 h/day was associated with diabetes, OR 1.25 (95% CI 1.12–1.40).; Sleeping ≥10 h/day was associated with diabetes, OR 1.79 (95% CI 1.46–2.20).
National Health Interview Survey, 2010 (379) | Age 18–85 years | 29,818 (15% non-Hispanic black) | Self-reported diabetes | In non-Hispanic whites, sleeping ≤5 h or ≥9 h was associated with diabetes, OR 1.87 (95% CI 1.57–2.24) and OR 2.33 (95% CI 1.98–2.73), respectively.; In non-Hispanic blacks, the corresponding ORs were 1.66 (95% CI 1.19–2.30) and 1.68 (95% CI 1.21–2.33), respectively.; Greater diabetes risk was seen in non-Hispanic black short and long sleepers compared to non-Hispanic whites.

CI, confidence interval; h, hour; NHANES, National Health and Nutrition Examination Survey; OR, odds ratio; PR, prevalence ratio.

SOURCE: References are listed within the table.

TABLE 25.3 Prospective Studies Exploring the Relationship Between Self-Reported Sleep Duration and Incident Diabetes

STUDY/LOCATION, YEARS (REF.) | POPULATION | SAMPLE SIZE | FOLLOW-UP (YEARS) | OUTCOME AND ASSESSMENT | RESULTS
Nurses’ Health Study, 1986–1996 (17) | Age 30–55 years | 70,026 | 10 | Questionnaire: symptoms of diabetes, plus FPG ≥140 mg/dL or random glucose ≥200 mg/dL, two elevated glucose levels on two occasions (fasting or random), or use of hypoglycemic medication | Sleeping ≤5 h/day was associated with increased diabetes risk, RR 1.57 (95% CI 1.28–1.92), but became nonsignificant after adjusting for BMI.; Sleeping ≤5 h/day was associated with increased risk of symptomatic diabetes, even after adjusting for BMI, RR 1.34 (95% CI 1.04–1.72).; Sleeping ≥9 h/day was associated with diabetes risk, RR 1.29 (95% CI 1.05–1.59).
Insulin Resistance Atherosclerosis Study, 1992–1999 (18) | Multiethnic: non-Hispanic white, African American, and Hispanic; age 40–69 years | 900 | 5 | Report of using diabetes medications; OGTT in those not taking diabetes medication—diabetes defined as 2-hour glucose value ≥200 mg/dL | Sleeping ≤7 h/night was associated with diabetes risk, OR 2.36 (95% CI 1.21–3.79) in non-Hispanic whites and Hispanics, but not in African Americans.; Sleeping ≥9 h/night was not associated with diabetes risk.
Sweden, 1969–2001 (19) | Mean age 46.8 years | 1,462 | 32 | Report of physician diagnosis of diabetes or use of medication, FPG ≥140 mg/dL on two separate occasions, or diagnosis documented in death certificate | No association between sleep duration (number of hours or quintiles of long versus short sleep) and diabetes risk.
NHANES I, 1982–1984, 1986–1987, and 1992 (20) | Mean age 56.1 years | 8,992 | 8–10 | Report of diabetes diagnosis by physician, hospital diagnosis, or cause of death | Sleeping ≤5 h/day was associated with increased diabetes risk, OR 1.47 (95% CI 1.03–2.09).; Sleeping ≥9 h/day was associated with diabetes risk, OR 1.52 (95% CI 1.06–2.18).
The 45 and UP Study, 2007–2010 (21) | Australian prospective cohort, mean age 62.3 years | 241,949 | 2–3 | Hospital admissions data and mortality data | Sleeping <6 h/day was associated with increased diabetes risk, HR 1.29 (95% CI 1.08–1.53).; Sleeping ≥9 h/day was not associated with diabetes risk.
Finnish Diabetes Prevention Study, 1993–2000 (22) | Mean age 55.2 years | 522 | 7 | OGTT with FPG ≥140 mg/dL or 2-hour glucose value ≥200 mg/dL | Sleeping ≤6.5 h/day was not associated with diabetes risk.; Sleeping 9–9.5 h and ≥10 h were associated with diabetes risk in the control group, HR 2.29 (95% CI 1.38–3.80) and HR 2.74 (95% CI 1.67–4.50), respectively. These sleep durations were not associated with diabetes risk in the lifestyle intervention group.
European Prospective Investigation into Cancer and Nutrition (EPIC)-Potsdam Study, Germany, 2004–2007 (23) | Age 35–65 years | 23,620 | 7.8 | Report of diabetes diagnosis verified by chart review | No associations were found between sleep duration and diabetes risk.
National Institutes of Health-AARP Diet and Health Study, 1996–2006 (24) | Age 50–71 years | 174,542 | 3–10 | Report of diabetes diagnosis by physicians | Sleeping <5 h and 5–6 h were associated with diabetes risk, OR 1.46 (95% CI 1.31–1.63) and OR 1.11 (95% CI 1.06–1.16), respectively.; Sleeping ≥9 h was associated with diabetes risk, OR 1.11 (95% CI 0.99–1.24).
Massachusetts Male Aging Study, 1987–2004 (25) | Age 40–70 years | 1,139 | 15–16 | Report of diabetes diagnosis by physician | Sleeping ≤5 h was associated with diabetes risk, RR 1.95 (95% CI 0.95–4.01). This became nonsignificant after adjusting for testosterone level.; Sleeping >8 h was associated with diabetes risk, RR 3.12 (95% CI 1.53–6.37), and remained significant after adjusting for testosterone.
High-risk and Population Strategy for Occupational Health Promotion Study (HIPOP-OHP), 1999–2004 (26) | Mean age 38.2 years | 6,509 | 4.2 | Report of diabetes diagnosis or using medication, FPG ≥140 mg/dL, or random glucose ≥200 mg/dL | No associations were found between sleep duration and diabetes risk.
Sweden, 1983–1995 (27) | Age 45–65 years | 2,663 | 12 | Questionnaire ascertained by using two questions | Sleeping ≤5 h was associated with diabetes risk in men only, RR 2.8 (95% CI 1.1–7.3).; No associations were found between sleep duration and diabetes risk in women.
Millennium Cohort by the Department of Defense, 2001–2007 (28) | Mean age 36.7 years | 47,093 | 6 | Report of diabetes diagnosis | Sleeping <5 h and 5 h were associated with increased diabetes risk, OR 2.04 (95% CI 1.49–2.81) and OR 1.46 (95% CI 1.15–1.84), respectively.; Sleeping ≥8 h was not associated with diabetes risk.
Japan, 2003–2008 (29) | Government employees in Sapporo, Japan, age 35–55 years | 3,570 | 3–5 | Having been prescribed diabetes medication or FPG ≥126 mg/dL | Sleeping ≤5 h was associated with diabetes risk, OR 5.37 (95% CI 1.38–20.91), in those without family history of diabetes.; No association was found in those with family history of diabetes.
Quebec Family Study, 1989–2001 (30) | Mean age 38.6 years | 276 | 6 | Type 2 diabetes, defined as FPG ≥126 mg/dL, 2-hour glucose value ≥200 mg/dL after OGTT, or use of insulin or oral hypoglycemic agents; IGT, defined as 2-hour glucose value ≥140 mg/dL in those not meeting diabetes criteria | Sleeping ≤6 h was associated with type 2 diabetes/IGT risk, RR 2.78 (95% CI 1.61–4.12).; Sleeping ≥9 h was associated with type 2 diabetes/IGT, RR 2.54 (95% CI 1.42–3.53).
Spain, 1997–2010 (31) | Population-based study, age 18–65 years | 1,145 | 11 | Fasting and 2-hour glucose values from OGTT | Sleeping ≤7 h compared to ≥8 h was associated with diabetes at 6-year follow-up, OR 1.96 (95% CI 1.10–3.50). The effect was not independent of obesity.; No association was found at 11-year follow-up.; Sleeping ≥10 h versus 7–9 h was not associated with diabetes.
Study by the Niigata Association of Occupational Health in Niigata, Japan, 1999–2012 (32) | Occupational health participants, Japan, age 18–83 years | 38,987 | 8 | FPG ≥126 mg/dL, self-reported diabetes diagnosis, or A1c level ≥6.5% | Sleeping <5.5 h and 5.5–<6.5 h were associated with diabetes, OR 1.53 (95% CI 1.19–1.97) and OR 1.25 (95% CI 1.10–2.42), respectively.; The effect was found mainly in those age ≤45 years, but not age ≥60 years.

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; BMI, body mass index; CI, confidence interval; FPG, fasting plasma glucose; h, hour; HR, hazard ratio; IGT, impaired glucose tolerance; NHANES, National Health and Nutrition Examination Survey; OGTT, oral glucose tolerance test; OR, odds ratio; RR, relative risk.

SOURCE: References are listed within the table.

Despite well-documented evidence for a causal relationship between sleep insufficiency and glucose metabolism, not a single interventional study to date has explored the role of sleep extension in diabetes prevention or treatment.

## Sleep Fragmentation, Shallow Sleep, and Insomnia

Sleep fragmentation is a hallmark of poor sleep quality that can be objectively assessed by low sleep efficiency (a ratio of time spent asleep versus time in bed) or by a long cumulated “wake time after sleep onset [WASO]” by polysomnography (PSG), the “gold standard” diagnostic test used to study sleep patterns and circadian rhythms in the medical setting. (PSG is described in more detail in the section Obstructive Sleep Apnea: Disease Definition and Diagnosis.) Actigraphy recordings, from a device that is worn on the wrist for a week or more and is less cumbersome, also provide good estimations of sleep efficiency.

Even in the absence of sleep fragmentation, shallow sleep, as reflected polygraphically from PSG by a low amount of deep NREM sleep (also known as SWS), has also been shown to be associated with adverse metabolic consequences. A laboratory study of healthy volunteers demonstrated that SWS suppression without changes in total sleep duration results in abnormal glucose metabolism. Suppression of SWS using acoustic stimuli for three nights resulted in a 25% decrease in insulin sensitivity as assessed by minimal model analysis of a frequently sampled IVGTT (40) without a compensatory increase in insulin secretion as assessed by the acute insulin response to intravenous glucose (Figure 25.1) (41). The acoustic stimuli were calibrated as to not induce full arousals and thus not affect sleep efficiency. In a similar study, sleep fragmentation by acoustic stimuli and mechanical vibrations for two full nights was associated with a 25% decrease in insulin sensitivity (Figure 25.1) (42). The experimental manipulation resulted in a marked decrease of SWS and also of other sleep stages.

Insomnia is one of the manifestations of subjective poor sleep quality. According to Diagnostic and Statistical Manual of Mental Disorders-V criteria, insomnia symptoms include one or more of the following: a report of difficulty initiating sleep, difficulty maintaining sleep, early-morning awakening with inability to return to sleep, or a report of unrefreshing sleep (43). Multiple cross-sectional studies in the United States have found a significant association between poor sleep quality or insomnia symptoms and prediabetes or diabetes (Table 25.4) (44,45,46,47,48). To date, 11 of 12 prospective studies have linked poor sleep quality to incident diabetes (Table 25.5) (19,26,27,28,29,49,50,51,52,53,54,55). One of the largest studies, conducted in U.S. military personnel, confirmed the association between trouble sleeping and diabetes risk (odds ratio [OR] 1.21, 95% CI 1.03–1.42) (28). Meta-analyses, pooling five of these studies, revealed that self-reported difficulty in maintaining sleep predicted the development of diabetes with a relative risk of 1.84 (total 24,192 participants), while self-reported difficulty in initiating sleep was associated with an increased relative risk of 1.57 (total 18,213 participants) (33). By comparison, estimates of the relative risk of developing diabetes associated with a family history of type 2 diabetes have ranged from 1.7 to 2.3 (56,57,58,59,60), with only one study in South African blacks estimating the relative risk at a substantially higher value of 4.1 (61). Thus, the relative risk of incident diabetes in individuals reporting insufficient sleep or difficulty initiating or maintaining sleep is of the same order of magnitude as the relative risk imparted by having a family history of type 2 diabetes, usually considered as one of the strongest predictors of diabetes risk. Interestingly, one study also found an association of poor sleep quality and an increased risk of autoimmune diabetes (53).

TABLE 25.4 Cross-Sectional Studies Exploring Associations Between Sleep Quality and Prediabetes or Diabetes

STUDY/LOCATION, YEARS (REF.) | POPULATION | SAMPLE SIZE | OUTCOME | RESULTS
NHANES, 2005–2006, 2007–2008 (44) | Age ≥30 years | 2,285 | Clinically identified prediabetes, defined as FPG 100–125 mg/dL, plus physician diagnosis of prediabetes | Trouble maintaining sleep ≥5 times/month was associated with clinically identified prediabetes, OR 3.50 (95% CI 1.30–9.45).; Waking up too early ≥5 times/month was associated with clinically identified prediabetes, OR 2.69 (95% CI 1.21–5.98).
NHANES, 2009–2010 (45) | Age >40 years | 3,668 | Diabetes, defined as FPG >125 mg/dL, A1c >6.4%, or 2-hour glucose >199 mg/dL, post 75 g glucose challenge | Sleep disturbance (i.e., reported to health professional that they had trouble sleeping) was associated with diabetes, OR 1.36 (95% CI 1.06–1.73).
National Sleep in America Survey, 2003 (46) | Age 55–84 years | 1,506 | Self-reported diabetes | Insomnia symptoms were not associated with diabetes.
Detroit, Michigan, NR (47) | Community-based sample, age 18–65 years | 3,282 (621 had PSG) | Self-reported diabetes | Insomnia symptoms were associated with diabetes, OR 1.40 (95% CI 1.05–2.00).; Sleep efficiency obtained from PSG was not different in those with or without diabetes.
Penn State Cohort, NR (48) | Age ≥20 years | 1,741 | Diabetes, defined as FPG ≥126 mg/dL or use of medication | Chronic insomnia for ≥1 year was associated with diabetes, OR 1.84 (95% CI 1.05–3.20).; The risk was highest in those with PSG-measured sleep duration ≤5 h, OR 2.95 (95% CI 1.24–7.05).; Poor sleep (difficulty falling asleep or staying asleep, early final awakening, or unrefreshing sleep) without insomnia complaint was not associated with diabetes.

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CI, confidence interval; FPG, fasting plasma glucose; NHANES, National Health and Nutrition Examination Survey; NR, not reported; OR, odds ratio; PSG, polysomnogram.

SOURCE: References are listed within the table.

TABLE 25.5 Prospective Studies Exploring the Relationship Between Sleep Quality or Insomnia Symptoms and Incident Prediabetes or Diabetes

STUDY/LOCATION, YEARS (REF.) | POPULATION | SAMPLE SIZE | FOLLOW-UP (YEARS) | SLEEP ASSESSMENT | OUTCOME AND ASSESSMENT | RESULTS
Stockholm Diabetes Prevention Program, Sweden, 1992–2006 (49) | Mean age 47 years | 5,227 | 8–10 | Reported sometimes or frequent insomnia | Prediabetes, defined as FPG 110–125 mg/dL or 2-hour glucose value 140–199 mg/dL after 75 g OGTT or both; Diabetes, defined as FPG ≥126 mg/dL or 2-hour glucose value ≥200 mg/dL | Men with high insomnia symptoms had increased risk of prediabetes/diabetes compared to low insomnia symptoms, OR 2.0 (95% CI 1.2–3.4).; No association was found in women.
Japan, 1984–1992 (50) | Male employees of electrical plant | 2,649 | 8 | Reported difficulty initiating or maintaining sleep | FPG ≥144 mg/dL or 2-hour glucose value ≥200 mg/dL after 75 g OGTT | High frequency of difficulty initiating sleep (often or almost every day) was associated with diabetes, HR 2.98 (95% CI 1.36–6.53).; Difficulty maintaining sleep was associated with diabetes, HR 2.23 (95% CI 1.08–4.61).
Germany, 1984–1998 (51) | Population-based cohort in Southern Germany, age 25–74 years | 8,269 | 7.5 | Reported difficulty initiating or maintaining sleep | Self-reported diabetes diagnosis and verified by chart review | Difficulty maintaining sleep was associated with diabetes, HR 1.60 (95% CI 1.05–2.45) in men and HR 1.98 (95% CI 1.20–3.20) in women.; Difficulty initiating sleep was not associated with diabetes.
Malmo Preventive Project, Sweden, 1974–1996 (52) | Age 35–51 years | 6,599 | 14.8 | Reported difficulty initiating sleep and regular use of hypnotic drugs | Self-reported diabetes diagnosis or use of medication. A subgroup of 1,551 subjects received a fasting blood test (diabetes diagnosed when fasting whole blood glucose was ≥6.1 mmol/L). | Difficulty falling asleep or regular use of hypnotics was associated with diabetes, OR 1.52 (95% CI 1.05–2.20).
Norwegian HUNT study, 1984–2008 (53) | Mean age 43.5 years | 53,394 | 11–22 | Symptoms of insomnia per DSM-IV criteria | Type 2 diabetes: report of diabetes diagnosis with verification by another interview on history and treatment; Autoimmune diabetes: GAD Ab and C-peptide level | Insomnia symptoms were associated with type 2 diabetes in men, HR 1.25 (95% CI 1.08–1.44), but not in women.; Insomnia symptoms were associated with autoimmune diabetes in men, HR 1.83 (95% CI 1.05–3.20), but not in women.
GAZEL Cohort study, 1990–2009 (54) | Employees of the French national electric and gas company, mean age 45 years | 16,989 | 19 | Questionnaire using Nottingham Health Profile^*^ | Self-report of diabetes diagnosis | Sleep disturbances were associated with diabetes, both in men, HR 1.59 (95% CI 1.15–2.20), and women, HR 2.18 (95% CI 1.37–3.45).
High-risk and Population Strategy for Occupational Health Promotion Study (HIPOP-OHP), 1999–2004 (26) | Mean age 38.2 years | 6,509 | 4.2 | Reported difficulty initiating or maintaining sleep | Report of diabetes diagnosis or using diabetes medication or FBG ≥126 mg/dL or random plasma glucose ≥200 mg/dL | Difficulty initiating sleep was associated with diabetes, HR 1.42 (95% CI 1.05–1.91) for a medium frequency and HR 1.61 (95% CI 1.00–2.58) for a high frequency.; Difficulty maintaining sleep was not associated with diabetes.
Sweden, 1983–1995 (27) | Population-based study, age 45–65 years | 2,663 | 12 | Self-reported sleep duration, difficulty initiating or maintaining sleep | Self-reported diabetes diagnosis by questionnaire, ascertained by using two questions | Difficulty maintaining sleep was associated with diabetes in men, RR 4.8 (95% CI 1.9–12.5), but not in women.; Difficulty initiating sleep was not associated with diabetes.
Millennium Cohort by the Department of Defense, 2001–2007 (28) | Mean age 36.7 years | 47,093 | 6 | Reported trouble falling asleep or staying asleep | Self-reported diabetes diagnosis | Trouble sleeping was associated with diabetes, OR 1.21 (95% CI 1.03–1.42).
Japan, 2003–2008 (29) | Government employees, age 35–55 years | 3,570 | 3–5 | Poor sleep quality^†^ | Having been prescribed diabetes medication and/or FPG ≥126 mg/dL | Awakening during the night and unsatisfactory overall quality of sleep were associated with diabetes, OR 5.03 (95% CI 1.43–17.64) and OR 6.7 (95% CI 2.09–21.87), respectively, in those without family history of diabetes.; No associations were found in those with family history of diabetes.
Hong Kong, 2003–2010 (55) | Population-based study of Hong Kong Chinese, mean age 46.3 years | Non-restorative sleep: 2,291 | 5 | Non-restorative sleep (morning unfreshness after getting up ≥3 times/week over the past 12 months) | Self-reported diabetes diagnosis | Non-restorative sleep was associated with diabetes, OR 2.63 (95% CI 1.23–5.63).
Sweden, 1968–2001 (19) | Cohort study of women, mean age 46.8 years | 1,462 | 32 | Sleep problems, defined as having reported sleep problems and/or having consulted a doctor for sleep problems and/or hospital admission for this reason, use of sleep medication | Self-reported of diabetes diagnosed by physician or use of diabetes therapy or FPG ≥126 mg/dL on two occasions or more | Sleep complaints or use of sleep medications were not associated with diabetes.

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CI, confidence interval; DSM-IV, Diagnostic and Statistical Manual of Mental Disorders-IV; FBG, fasting blood glucose; FPG, fasting plasma glucose; GAD Ab, glutamic acid decarboxylase antibody; HR, hazard ratio; OGTT, oral glucose tolerance test; OR, odds ratio; RR, relative risk.

* Three or more of the following: I take a tablet to help me sleep; I lie awake most of the night; I sleep badly at night; It takes me a long time to fall asleep; or I wake up in the early hours of the morning.

† Two or more of the following: problems with sleep induction, awakening during the night, final awakening earlier than desired, insufficient sleep, or overall poor sleep quality.

SOURCE: References are listed within the table.

Only a few cross-sectional studies have examined the relationship between sleep quality and glycemic control in patients with type 2 diabetes. The largest study in the United States included 161 African American patients and found that in those with at least one diabetic complication (i.e., retinopathy, neuropathy, nephropathy, cardiovascular, or cerebrovascular diseases), there was a graded relationship between glycemic control as assessed by A1c and the score on the Pittsburgh Sleep Quality Index (PSQI) (34). Specifically, a 5-point increase in PSQI score predicted an elevation of A1c level of 1.9% above the median. Another cross-sectional study of 46 Taiwanese patients found an association between poor glycemic control (defined as A1c ≥7% [≥53 mmol/mol]) and poor sleep quality (PSQI ≥8), as well as poor sleep efficiency (62). Similarly, poor sleep quality as assessed by questionnaire in 551 Chinese type 2 diabetes patients found an association between lower sleep quality and higher insulin resistance as measured by HOMA-IR (63).

A few studies have utilized objective measurement of sleep quality. Knutson et al. reported a cross-sectional association between an objective estimation of sleep quality and markers of glucose metabolism in participants of the Coronary Artery Risk Development in Young Adults (CARDIA) study (38). The sleep parameters were derived from actigraphy recordings, which have been shown to be well correlated with those obtained by PSG (64). While there were no correlations between sleep and metabolic variables in nondiabetic participants, sleep fragmentation and insomnia were associated with significantly higher fasting glucose, insulin, and HOMA levels in diabetic participants (38). Another study conducted in Italy, involving 47 patients with type 2 diabetes, reported that A1c correlates inversely with sleep efficiency as measured by actigraphy (39). Interestingly, in the NHANES 2005–2006, a study of 958 adults with prediabetes (fasting glucose 100–125 mg/dL [5.55–6.94 mmol/L], 2-hour oral glucose tolerance values of 140–199 mg/dL [7.77–11.04 mmol/L], or A1c 5.7%–6.4% [39–46 mmol/mol]) did not find a relationship between insomnia symptoms and A1c levels (65). However, those with insomnia symptoms were less active as measured by steps walked during the 2-day recordings. The findings suggest that insomnia in adults with prediabetes may be a barrier to adopting an active lifestyle.

Despite the link between poor sleep quality and diabetes risk or poor glycemic control in patients with type 2 diabetes, there has not been a single study so far exploring whether improving sleep quality may be a viable strategy to prevent diabetes or reduce its severity.

### Pathways Involved in the Adverse Metabolic Impact of Insufficient Sleep and Poor Sleep Quality

Laboratory studies in healthy humans have provided evidence for the implication of multiple pathways in the link between reduced sleep duration and/or quality, insulin resistance, and hyperglycemia (Figure 25.2) (2).

#### Decreased Brain Glucose Utilization During Waking Hours

The brain utilizes glucose in an insulin-independent manner and is responsible for at least 50% of total glucose utilization in the fasting state. The rate of cerebral glucose metabolism as measured by positron emission tomography and ^18^Fluorine-2-deoxyglucose following a 24-hour period of total sleep deprivation has been found to be significantly decreased, especially in several cortical and subcortical areas (66). This is in agreement with the findings of a sleep debt study that revealed a 30% reduction in glucose effectiveness, an index of insulin-independent glucose disposal (8).

#### Increased Sympathetic Nervous System Activity

Sleep deprivation and sleep fragmentation lead to a shift in sympathovagal balance toward an increase in sympathetic nervous system activity as reflected by lower heart rate variability (8,41,42). Increased sympathetic nervous system activity has inhibitory effects on insulin secretion and promotes insulin resistance and the development of the metabolic syndrome (67,68). In addition, some studies have documented increased serum and urine norepinephrine and epinephrine concentrations following sleep deprivation (11,12,69). These hormones promote gluconeogenesis.

#### Alterations in the Hypothalamic-Pituitary-Adrenal Axis and Growth Hormone

Several studies observed an increase in salivary and serum cortisol levels following sleep deprivation, particularly in the evening and early part of the night, at the time when the levels are normally very low following the normal circadian pattern (8,12,70,71). In one study, there was no change in corticotropin (ACTH) level, suggesting an enhanced adrenal reactivity (70). Evening elevations of cortisol may promote morning insulin resistance (72). An increase in morning serum cortisol levels was also reported after sleep fragmentation (73). In a sleep debt study, growth hormone secretion was found to increase prior to sleep onset and to limit the amplitude of post-sleep onset growth hormone release (9). Prolonged nighttime exposure to growth hormone may promote hyperglycemia.

FIGURE 25.2 Pathways Linking Sleep Insufficiency and Fragmentation to Abnormal Glucose Metabolism and Type 2 Diabetes

Flow chart showing pathways in which short sleep duration and sleep fragmentation lead to decreased beta-cell function and increased insulin resistance, and ultimately to type 2 diabetes

SOURCE: Reference 2, copyright © 2014 New York Academy of Sciences, reprinted with permission

#### Increase in Systemic Inflammatory Response

Inflammatory responses to sleep deprivation have been reviewed in detail (74). Multiple studies have demonstrated increases in leukocyte and monocyte counts (75,76,77), as well as elevations in the levels of proinflammatory cytokines, including interleukin (IL)-1 beta, IL-6, IL-17, tumor necrosis factor (TNF)-alpha, and high sensitivity C-reactive protein (hsCRP) (13,78,79,80,81). Increased proinflammatory cytokines have been linked to insulin resistance (82). Some studies, however, did not observe an association between alterations in the circulating levels of some of these cytokines and sleep disturbances, possibly partly due to variability of baseline levels within the population, as well as timing of specimen collection relative to the circadian cycle (74).

#### Alterations in Appetite-Regulating Hormones and Increased Obesity Risk

Appetite-regulating hormones, including leptin, which is one of the satiety hormones, and ghrelin, which is a hunger hormone, have been studied in the context of sleep restriction experiments. The first study that assessed these changes involved two nights of 4 hours in bed versus two nights of 10 hours in bed in healthy, normal-weight young men (83). During sleep restriction, leptin decreased by 18% and ghrelin increased by 28%. These changes were associated with a 23% increase in hunger ratings and a 33% increase in appetite for carbohydrate-rich foods. More than 10 subsequent studies have explored these hormonal changes in response to sleep restriction with some variations in participants’ characteristics (i.e., adiposity and sex distribution), severity of sleep restriction, blood sampling methodology, and dietary protocols (ad libitum food access or controlled caloric consumption) (84,85). Not surprisingly, since leptin levels are highly sensitive to energy balance and modulated by sex and adiposity, the findings have been inconsistent, with decreased (83,86,87,88), unchanged (89,90), or increased (14,91,92,93) concentrations. However, most of the studies that utilized multiple blood samplings in normal-weight men under conditions of controlled food intake consistently revealed a reduction in leptin amplitude or mean levels, suggesting that the discrepancies may, at least in part, be due to modulation of leptin secretion by obesity, sex, and food intake. Whether the results obtained in short-term laboratory studies may be extrapolated to real-life conditions is debatable. In a field study of 80 obese adults, no associations were found between leptin levels and sleep duration or quality (94). In contrast, the Wisconsin Sleep Cohort Study (1,024 participants) found an association between reduced leptin levels, along with elevated ghrelin levels and increased body mass index (BMI), in those reporting sleeping 5 hours compared to 8 hours (95).

Multiple studies documented increased ghrelin levels along with increased hunger in response to partial sleep restriction (83,91,93), as well as increased caloric intake, mostly from snacks. Several studies have observed that the excessive caloric consumption was mostly from carbohydrate-rich foods, although increased intake of fat or of all macronutrients has also been reported (96,97,98,99,100). However, similar to the findings regarding leptin levels, not all studies observed increased ghrelin levels (11,97,101). Two studies utilizing functional magnetic resonance imaging revealed increased neuronal activity in certain brain areas involved in the reward system in response to presentation of food stimuli after total and partial sleep restriction (102,103). These imaging findings are consistent with a report showing an increase in the levels of circulating endocannabinoid 2-arachidonoylglycerol (2-AG) after three days of sleep restriction compared to normal sleep (89).

Since sleep restriction provides more wake time, it has been suggested that the caloric need of extended wakefulness may counterbalance the increase in hunger and food intake. Several studies have addressed changes in energy expenditure following sleep restriction. Surprisingly, three independent studies failed to detect an increase in energy expenditure assessed by the doubly labeled water method in individuals who underwent experimental partial sleep restriction (96,97,98). However, when the subjects were confined to a calorimetry room in order to monitor minute-to-minute energy expenditure during normal sleep and total sleep deprivation (104), the caloric cost per hour of wakefulness under sedentary conditions compared to sleep averaged only 17 Kcal, suggesting that the stimulation of hunger and food intake far exceeds the caloric need of extended wakefulness. A study involving 5 days of partial sleep restriction, similar to a work week, under controlled laboratory conditions indeed observed that the approximate 5% increase in daily energy expenditure was overcompensated by energy intake, particularly at night, resulting in significant weight gain (99). Additionally, there is evidence that the sleepiness and fatigue associated with insufficient sleep may result in a reduction in voluntary physical activity (105,106).

Collectively, these changes in appetite regulation in favor of increased hunger and food intake without commensurate increase in energy expenditure place individuals at risk for obesity. These results are supported by multiple prospective studies that found a significant association between short sleep and greater weight gain in both adults and children (107,108,109,110).

#### Abnormal Adipocyte Function

Adipocytes play a pivotal role in the regulation of energy balance and appear to play an important role in the changes in energy balance in response to sleep restriction (111). Leptin is released primarily from subcutaneous fat depot in direct proportion to insulin-stimulated glucose uptake and total subcutaneous fat mass (112). Increased sympathetic nervous activity leads to stimulation of lipolysis and increased free fatty acids which could lead to insulin resistance (113). A randomized crossover trial of 4 days of sleep restriction (4.5 hours per night) versus 4 days of normal sleep (8.5 hours per night) in healthy, young, lean men studied under controlled conditions of caloric intake and physical activity showed an increase in nocturnal free fatty acid levels that was correlated with the reduction in insulin sensitivity (114). In addition, elevated levels of glucocorticoids facilitate visceral fat accumulation, increased lipolysis, and insulin resistance. Molecular mechanisms involved in insulin signaling in adipocytes collected from individuals who were sleep restricted were examined by Broussard et al. (10) in a subset of the participants in the randomized crossover study of 4 days with 4.5 hours in bed versus 8.5 hours in bed. Subcutaneous fat biopsy under restricted sleep conditions revealed a 30% reduction in the ability of insulin to increase levels of phosphorylated Akt (also known as protein kinase B), a crucial early step in the insulin signaling pathway, compared to during normal sleep conditions. This impaired cellular insulin sensitivity paralleled the decrease in total body insulin sensitivity as assessed by IVGTT.

In summary, a large body of evidence supports a causal relationship between sleep insufficiency and sleep fragmentation and alterations in multiple physiologic pathways, resulting in abnormal glucose metabolism, increased diabetes risk, and possibly contributing to poor glycemic control in individuals who have prediabetes or diabetes. Further research studies should explore whether optimizing sleep duration and quality will, in the long term, result in decreased diabetes risk or improved glycemic control in patients with established type 2 diabetes.

### Pathways Involved in the Adverse Metabolic Impact of Long Sleep Duration

In contrast to short sleep duration, the mechanisms linking long sleep duration and abnormal glucose metabolism are poorly understood. One of the limitations is that most, if not all, studies documenting an adverse metabolic impact of long sleep (typically >8–9 hours per night) have been based on self-reported sleep duration. Additionally, it has been speculated that long sleepers are actually poor sleepers who extend their time in bed to try to compensate for poor sleep quality (115). Another possibility is that long sleepers suffer from fatigue resulting from an undiagnosed preclinical condition. In a study of type 2 diabetes patients, long sleepers (≥8.5 hours per night) were more likely to have depressive symptoms and to be more physically inactive compared to those who reported sleeping 6.5–7.4 hours per night (35). Increased sedentarity, a correlate of long sleep, could also have adverse cardiometabolic effects. A prerequisite to the identification of putative mechanisms that could mediate adverse effects of long sleep is the demonstration that these effects are still present when sleep duration is assessed objectively, rather than by self-report.

## Obstructive Sleep Apnea

### Disease Definition and Diagnosis

OSA is a common sleep disorder that is characterized by recurrent episodes of complete or partial collapse of the upper airway during sleep. The cessation or reduction in airflow is often associated with decreased oxygen saturation and/or arousal from sleep. Patients with OSA present with a constellation of nocturnal symptoms that include loud disruptive snoring, bed partner-reported breathing pauses (apneas), choking and gasping episodes during sleep, and frequent awakenings. Common daytime consequences include excessive daytime sleepiness, fatigue, irritability, and deficits in attention and memory. Epidemiologic data from several community- and population-based studies from North America, Europe, and Asia indicate that sleep apnea affects approximately 3%–7% of adult men and 2%–5% of adult women (Table 25.6) (116). However, the prevalence is likely to have increased due to the increasing obesity rates. For example, between 1988–1994 and 2007–2010, the prevalence in the Wisconsin Sleep Cohort increased by as much as 55% (117). In 2007–2010, the estimates of OSA prevalence in obese adults ranged between 33% and 77% in men and between 11% and 46% in women (117). Despite the increasing body of literature recognizing the adverse health consequences and public health impact of sleep apnea, a considerable number of affected individuals remain undiagnosed (118,119).

The diagnosis of OSA is based on an overnight sleep study or a polysomnogram (PSG). It involves simultaneous recordings of several electrophysiological signals, including the right and left electrooculograms, the submental electromyogram, and the electro encephalogram (EEG). Collectively, these physiological signals are used to distinguish wakefulness from sleep and assess the distribution of various sleep stages. In addition, breathing patterns are assessed with measurements of respiratory effort, airflow, and oxygen saturation. Airflow is recorded with an oronasal thermistor (a probe sensitive to temperature changes that occur with breathing) and/or a nasal cannula configured to monitor pressure changes in the nasal airway. The PSG also includes other measurements, such as continuous electrocardiography, which is used to detect occurrence of cardiac arrhythmias during sleep. The analysis of the PSG for OSA requires identification of abnormal or disordered breathing patterns during sleep. Two basic types of disordered breathing events are assessed: apneas and hypopneas (Table 25.7). An apnea is defined as the complete cessation of airflow for at least 10 seconds. A hypopnea is defined as a reduction in airflow that is associated with an EEG arousal or a decrease in oxygen saturation (120).

TABLE 25.6 Studies on the Prevalence of Obstructive Sleep Apnea

LOCATION, YEARS (REF.) | SAMPLE SIZE | ETHNICITY | SLEEP ASSESSMENT | PREVALENCE (%)
LOCATION, YEARS (REF.) | SAMPLE SIZE | ETHNICITY | SLEEP ASSESSMENT | Men | Women
U.S., 1988 (380) | 602 | White | Polysomnography | 4.0 | 2.0
U.S., NR (381) | 741 | White | Polysomnography | 3.3 | NA
U.S., NR (382) | 1,000 | White | Polysomnography | NA | 1.2
Australia, NR (383) | 485 | White | Respiratory polygraphy | 3.1 | NA
India, 1999–2000 (384) | 250 | Indian | Polysomnography | 7.5 | 4.5
China, 1997–1999 (385) | 258 | Chinese | Polysomnography | 4.1 | NA
China, 1998–2000 (386) | NR | Chinese | Polysomnography | NA | 2.1
Korea, 2001 (387) | 457 | Korean | Polysomnography | 4.5 | 2.3

NA, not applicable; NR, not reported.

SOURCE: Adapted from Reference 116, reprinted with permission of the American Thoracic Society. Copyright © 2008 American Thoracic Society. Proceedings of the American Thoracic Society is an official journal of the American Thoracic Society. References for individual studies are listed within the table.

TABLE 25.7 Types of Disordered Breathing Events During Sleep

TERM | DEFINITION
Disordered breathing event
Apnea | Cessation of airflow ≥10 seconds
Hypopnea | Reduction in airflow associated with oxygen desaturation and/or arousal
Type of disordered breathing event
Obstructive | An event with absence of airflow but with continued respiratory effort
Central | An event with absence of airflow and no respiratory effort
Mixed | An event that typically starts with a period that meets the criteria for a central event but ends with respiratory effort without airflow
Indices on disordered breathing severity
Apnea-Hypopnea Index | Number of apneas and hypopneas per hour of total sleep time
Apnea Index | Number of apneas per hour of total sleep time
Hypopnea Index | Number of hypopneas per hour of total sleep time
Central Apnea Index | Number of central apneas per hour of total sleep time

SOURCE: Original table constructed by N. M. Punjabi.

Disordered breathing events are further classified into obstructive, central, or mixed events. The classification of an abnormal breathing event is dependent on whether, in the absence of oronasal airflow, there is evidence of respiratory effort. An obstructive event is defined as the absence of airflow in the presence of continued effort. In contrast, a central event is defined as the absence of airflow without associated effort. Finally, a mixed event manifests characteristics of an obstructive and a central event. Mixed events typically start with a period that meets the criteria for a central event but end with increasing effort but without associated airflow. Figure 25.3 illustrates tracings of the three types of abnormal breathing patterns (obstructive, central, and mixed apneas) during sleep (121). PSG yields a quantification of episodes of apnea and hypopnea per hour of sleep, an apnea-hypopnea index (AHI). A diagnosis of OSA is made when the AHI is ≥5.

### Obstructive Sleep Apnea and Metabolic Dysfunction

In addition to reductions in sleep duration and quality, intermittent hypoxia is the hallmark of OSA. Only one experimental study in humans has examined the impact of intermittent hypoxemia on glucose metabolism. In this study, 13 healthy volunteers were subjected to 5 hours of intermittent hypoxia while awake, resulting in an average of 24.3 desaturation events per hour (122), equivalent to hypoxia in OSA of moderate severity (AHI ≥15–30). Insulin sensitivity and glucose effectiveness, as assessed by IVGTT, were reduced by 17% and 31%, respectively, without simultaneous increase in insulin secretion. These results suggest that hypoxic stress may have an intrinsic adverse impact on glucose metabolism and diabetes risk.

FIGURE 25.3 Types of Disordered Breathing Events

Three-minute recordings characteristic of obstructive, central, and mixed apneas during sleep. Traces shown represent oxyhemoglobin saturation, airflow, and thoracic and abdominal movement.

Tracing of 3 types of sleep apnea, including obstructive, central, and mixed apnea, each with a distinct pattern of oxyhemoglobin saturation, airflow, and thoracic and abdominal movement

SOURCE: Reference 121, copyright © 2013 Elsevier, reprinted with permission

Over the last two decades, a number of observational studies have demonstrated that OSA is associated with insulin resistance, glucose intolerance, type 2 diabetes, and the metabolic syndrome, independent of such factors as age, sex, race, BMI, and measures of visceral adiposity (Tables 25.8 and 25.9). Epidemiologic data from community- and population-based cohorts, including the Sleep Heart Health Study (123) and the Wisconsin Sleep Cohort Study (124), have shown that the severity of OSA, as assessed by the AHI, is directly associated with fasting hyperglycemia, glucose intolerance, and the prevalence of physician-diagnosed type 2 diabetes. Irrespective of the method used for assessing insulin sensitivity, a majority of published reports indicate that the severity of OSA (i.e., AHI) is inversely related to the degree of insulin sensitivity. Moreover, metrics of nocturnal hypoxemia (e.g., oxyhemoglobin desaturation and average oxygen saturation during sleep) strongly correlate with the degree of whole body insulin resistance (Table 25.8).

TABLE 25.8 Studies on the Association Between Obstructive Sleep Apnea and Measures of Insulin Resistance

YEARS (REF.) | STUDY SAMPLE | SAMPLE SIZE | SLEEP ASSESSMENT | INDEPENDENT VARIABLE | DEPENDENT VARIABLE | CONFOUNDERS ASSESSED | ASSOCIATION
NR (388) | OSA | 18 | Oximetry | ODI | Insulin resistance index from OGTT | BMI, age | +
1991–1993 (389) | OSA | 261 | PSG | AHI | I_0_ | BMI | +
NR (390) | OSA and controls | 66 | PSG | AHI | I_0_ | BMI, waist/hip ratio, age | −
1991 (391) | Primary care | 1,190 | Self-report | OSA symptoms | I_0_ | BMI, visceral fat, age | +
NR (392) | Healthy participants | 50 | MESAM^*^ | ODI | Insulin suppression test | BMI, age, sex, activity | −
NR (246) | OSA | 10 | PSG | AHI | Hyperinsulinemic clamp | BMI | −
NR (393) | OSA and controls | 60 | PSG | AHI | I_0_ and I_0_/G_0_ ratio | BMI, waist, hip, age, sex | +
NR (394) | OSA and controls | 37 | PSG | AHI | I_0_ | BMI, visceral fat | +
1996–1998 (395) | Hypertensive men | 116 | Edentec^*^ | ODI | I_0_ | BMI, waist/hip ratio, age | +
1999–2000 (396) | OSA | 270 | PSG | AHI | HOMA IR | BMI, waist, age | +
NR (397) | OSA | 20 | PSG | AHI | Hyperinsulinemic clamp | BMI, sex, age | +
NR (398) | Community sample | 151 | PSG | AHI | HOMA IR | BMI, waist, percent body fat | +
1998–2000 (399) | OSA and snorers | 595 | PSG | AHI | G_0_/I_0_ ratio | BMI, age | +
NR (400) | OSA and controls | 57 | PSG | AHI | Insulin sensitivity index from OGTT | BMI, waist/hip ratio, age | +
NR (401) | OSA and controls | 65 | PSG | AHI | HOMA IR | BMI, age | −
1994–1999 (123) | Community sample | 2,565 | PSG | AHI | HOMA IR | BMI, waist, age, sex | +
NR (402) | OSA | 213 | PSG | AHI | HOMA IR | BMI, visceral fat, age | +
NR (244) | OSA and controls | 42 | PSG | AHI | HOMA IR | BMI, waist, age | +
2003–2005 (245) | OSA and controls | 120 | PSG | AHI | HOMA IR | BMI, waist | −
NR (403) | OSA | 67 | PSG | AHI | HOMA IR | BMI, waist | −
2002–2004 (404) | Population sample | 400 | PSG | AHI | Insulin sensitivity index | Waist/hip ratio, age, activity | +
NR (405) | OSA | 98 | PSG | AHI | HOMA IR | BMI, sex, age | +
NR (406) | OSA and controls | 118 | PSG | AHI | Insulin sensitivity from IVGTT | BMI, waist, percent fat, age | +
NR (407) | OSA and controls | 98 | PSG | AHI | HOMA IR | BMI, age | +
NR (408) | OSA | 23 | PSG | AHI | HOMA IR | BMI | +

AHI, apnea-hypopnea index; BMI, body mass index; G_0_, fasting glucose; HOMA IR, homeostasis model assessment of insulin resistance; I_0_, fasting insulin; IVGTT, intravenous glucose tolerance test; NR, not reported; ODI, oxygen desaturation index; OGTT, oral glucose tolerance test; OSA, obstructive sleep apnea; PSG, polysomnogram. In the Association column, a plus sign (+) denotes a statistically significant association and a minus sign (-) denotes no significant association.

* Edentec and MESAM are portable sleep monitoring units.

SOURCE: References are listed within the table.

To date, nine prospective cohort studies, with approximately 65,000 participants, have been conducted to explore whether the presence of OSA, using objective sleep assessments, at baseline predicted incident diabetes during a follow-up, after adjusting for BMI or other measures of adiposity and other confounders (Table 25.10) (28,124,125,126,127,128,129,130,131). The studies varied in the methods and criteria used to diagnose OSA (pulse oximetry vs. full or limited PSG, and cutoff for AHI/oxygen desaturation index), verification of diabetes diagnosis, and duration of follow-up period (2.7–16 years). A meta-analysis including five of these studies (total 5,953 participants) revealed that moderate to severe OSA was associated with a significantly greater risk of developing diabetes, with a relative risk of 1.63 (95% CI 1.09–2.45), compared to those without OSA (132). In those with mild OSA (AHI <15), the relative risk was 1.22 (95% CI 0.91–1.63), but this was not statistically significant. These data strongly support the concept that the presence of moderate to severe OSA is a risk factor for diabetes development independent of other confounding factors.

TABLE 25.9 Studies on the Association Between Obstructive Sleep Apnea, Glucose Tolerance, Type 2 Diabetes, and the Metabolic Syndrome

YEARS (REF.) | STUDY SAMPLE | SAMPLE SIZE | SLEEP ASSESSMENT | INDEPENDENT VARIABLE | DEPENDENT VARIABLE | CONFOUNDERS ASSESSED | ASSOCIATION
NR (398) | Community sample | 151 | PSG | AHI | OGTT | BMI, waist, percent fat | +
1998–2000 (399) | OSA and snorers | 594 | PSG | AHI | OGTT | BMI, age | +
NR (400) | OSA and controls | 57 | PSG | AHI | OGTT | BMI, waist/hip ratio | +
1994–1999 (123) | Community sample | 1,930 | PSG | AHI | OGTT | BMI, waist, age, sex | +
2002–2004 (404) | Population sample | 400 | PSG | AHI | OGTT | Waist/hip ratio, age, activity | +
1994–1999 (409) | Community sample | 2,588 | PSG | AHI | OGTT | BMI, waist, age, sex | +
2004–2005 (410) | Population sample | 2,896 | Self-report | OSA symptoms | OGTT | BMI, age, sex | +
1994 (395) | Hypertensive men | 116 | Portable monitor | ODI | Diabetes prevalence | BMI, waist/hip ratio, age | +
1986–1996 (411) | Nurses’ Health Study | 69,852 | Self-report | OSA symptoms | Self-reported diabetes | BMI, age, menopause | +
1991–1994 (412) | Population sample | 295 | Self-report | Snoring | Metabolic syndrome | Age, smoking, activity, exercise | +
NR (413) | OSA and controls | 104 | PSG | AHI | Metabolic syndrome | BMI, age, smoking, alcohol | +
NR (414) | OSA | 87 | PSG | AHI | Metabolic syndrome | None | +
NR (415) | OSA | 819 | PSG | AHI | Metabolic syndrome | BMI, age | +
NR (416) | OSA and controls | 79 | Portable monitor | AHI | Metabolic syndrome | BMI, age, smoking | +
1997–1999 (417) | Community sample | 255 | PSG | AHI | Metabolic syndrome | BMI, age, sex | +
2004–2005 (418) | Population sample | 1,946 | Self-report | OSA symptoms | Metabolic syndrome | Age, sex, smoking | +
NR (419) | OSA | 98 | PSG | AHI | Metabolic syndrome | BMI | +
2002–2006 (420) | OSA and controls | 94 | PSG | AHI | Metabolic syndrome | BMI, visceral fat, sex | +
2004 (421) | Sleep clinic sample | 225 | PSG | AHI | Metabolic syndrome | BMI, age | +
1983–1987 (422) | OSA | 40 | PSG | Diabetes status | OSA prevalence | Age, BMI | +
1996–1998 (423) | Population sample | 593 | Self-report | Diabetes status | OSA prevalence | BMI, neck, sex | +
NR (424) | Diabetic patients | 938 | Self-report | Diabetes status | OSA prevalence | BMI, neck, age | +
2001 (425) | Population sample | 993 | Self-report | Glucose tolerance | OSA prevalence | BMI, waist, sex, activity | +
NR (137) | Diabetic patients | 279 | Portable monitor | Diabetes status | OSA prevalence | BMI, age | +
2005 (426) | Patients with the metabolic syndrome | 24 | PSG | Metabolic syndrome | OSA prevalence | None | +
2003–2007 (427) | Patients with the metabolic syndrome | 195 | Portable monitor | Metabolic syndrome | OSA prevalence | Age, sex, hypertension | +

AHI, apnea-hypopnea index; BMI, body mass index; NR, not reported; ODI, oxygen desaturation index; OGTT, oral glucose tolerance test; OSA, obstructive sleep apnea; PSG, polysomnogram. In the Association column, a plus sign (+) denotes a statistically significant association and a minus sign (-) denotes no significant association.

SOURCE: References are listed within the table.

In patients with an established diagnosis of type 2 diabetes, who were generally obese, OSA was shown to be highly prevalent, from a lowest estimate of 58% to a highest estimate of 86%, based on seven independent studies involving a total of 1,272 participants (Figure 25.4) (133,134,135,136,137,138,139). The weighted average was 67%.

This proportion is alarming given that, in 2011, 20.9 million Americans were estimated to have diabetes, which could possibly translate to as many as 14 million individuals suffering from both diabetes and OSA. Unfortunately, this highly prevalent comorbidity of type 2 diabetes often remains unrecognized. A retrospective analysis of 27 primary care practices involving 16,066 diabetes patients found that only 18% were diagnosed with OSA, suggesting that a majority of diabetic patients may not be diagnosed, and therefore, their OSA is left untreated (140).

TABLE 25.10 Prospective Studies on the Relationship Between Obstructive Sleep Apnea and Incident Diabetes

STUDY/LOCATION, YEARS (REF.) | POPULATION | SAMPLE SIZE | FOLLOW-UP (YEARS) | OSA ASSESSMENT | DIABETES ASSESSMENT | RESULTS
Connecticut, 2000–2005 (125) | Patients referred to the Veterans Affairs Sleep Center, mean age 61.5 years | 1,233 | 2.7 | AHI ≥8 by PSG | Fasting glucose >126 mg/dL, ascertained by chart review | OSA was associated with diabetes, HR 1.43 (95% CI 1.10–1.86).
Sweden, 1991–2007 (126) | Patients referred to sleep laboratory, mean age 48.2 years | 318 | 16 | 4% ODI ≥30 events/night using an oximetry, a nasal and oral airflow, and respiration and body movement monitoring | Self-reported diabetes diagnosis, verified by chart review | OSA was associated with diabetes in women, OR 11.78 (95% CI 1.14–121.7), but not in men.
Sweden, 1996–2008 (127) | Population-based, men who responded to postal questionnaires, mean age 57.5 years | 141 | 11.3 | AHI ≥5 by PSG | Self-reported diabetes diagnosis, verified by FPG ≥126 mg/dL | OSA was associated with diabetes, OR 4.4 (95% CI 1.1–18.1).
Australia, 1990–1995 (128) | Population-based study, mean age 53.1 years | 399 | 4 | RDI ≥5 from a 4-channel home monitoring device (heart rate, oxygen saturation, snoring, and body position) | Self-reported diabetes diagnosis, use of medication, or FPG ≥126 mg/dL | Moderate to severe OSA (RDI ≥15) was associated with diabetes, OR 13.45 (95% CI 1.59–114.11).
Japan, 2001–2007 (129) | Population-based study in five communities, mean age 57.6 years | 4,606 | 3 | 3% ODI ≥5 events/hour from a pulse oximetry | FPG ≥126 mg/dL, random glucose ≥200 mg/dL, or use of diabetes medications/insulin | Moderate OSA (ODI ≥15) was associated with diabetes, HR 1.69 (95% CI 1.04–2.76).
Wisconsin Sleep Cohort, 1988–1993 (124) | Mean age 49.0 years | 1,387 | 4 | AHI ≥5 by PSG | Self-reported diabetes diagnosis or FPG ≥126 mg/dL | No association between OSA and diabetes development
Millennium Cohort by the Department of Defense, 2001–2007 (28) | Mean age 36.7 years | 47,093 | 6 | Reported a physician diagnosis of OSA | Self-reported diabetes diagnosis | OSA was associated with diabetes, OR 1.78 (95% CI 1.39–2.28).
Australia, 2000–2012 (130) | Population-based study, mean age 59.7 years | 736 | 4.7 | Eight-channel, unattended, in-home PSG performed at the last visit | Self-reported diabetes diagnosis or use of medication or FPG ≥126 mg/dL or A1c ≥6.5% | Current severe OSA (AHI ≥30) was associated with diabetes, OR 2.6 (95% CI 1.1–6.1).; Current ODI ≥16 was associated with diabetes, OR 1.85 (95% CI 1.06–3.21).
Canada, 1994–2011 (131) | Patients referred to sleep lab | 8,678 | 5.6 | AHI ≥5 by PSG | At least one hospitalization record or at least two physician services claims bearing a diagnosis of diabetes within a 2-year period | AHI >30 was associated with diabetes, HR 1.31 (95% CI 1.07–1.61).

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; AHI, apnea-hypopnea index; CI, confidence interval; FPG, fasting plasma glucose; HR, hazard ratio; ODI, oxygen desaturation index; OR, odds ratio; OSA, obstructive sleep apnea; PSG, polysomnogram; RDI, respiratory disturbance index.

SOURCE: References are listed within the table.

FIGURE 25.4 Prevalence of Obstructive Sleep Apnea Among Persons With Type 2 Diabetes

Obstructive sleep apnea was assessed by polysomnogram in all studies.

Bar chart showing the prevalence of obstructive sleep apnea among people with type 2 diabetes ranged from 58% to 86% in 7 separate studies

SOURCE: References 133, 134, 135, 136, 137, 138, and 139, as listed within the figure.

Similar to nondiabetic populations, the severity of untreated OSA is associated with poorer glycemic control in diabetic populations. Aronsohn et al. utilized PSG to assess OSA severity in 60 diabetic patients (133). There was a graded relationship between the severity of untreated OSA as measured by AHI and higher A1c levels after adjusting for age, sex, race, BMI, years of diabetes, numbers of diabetes medications, exercise, and total sleep time, with an effect size as large as that associated with the impact of diabetes drugs. Another cross-sectional study in 52 diabetic patients also found that increased severity of OSA was associated with increased A1c levels, after adjusting for age, sex, BMI, diabetes duration, and insulin dose (139). Adjusted mean A1c was 8.6% (70 mmol/mol) in those without OSA, 9.4% (79 mmol/mol) in mild OSA, 10.6% (92 mmol/mol) in moderate OSA, and 9.9% (85 mmol/mol) in severe OSA. However, not all of the studies supported a link between OSA severity and glycemic control. The Sleep AHEAD study, involving obese type 2 diabetes patients, analyzed the relationship between sleep and metabolic parameters in 305 subjects (141). The only significant association was an inverse correlation between fasting glucose levels and sleep efficiency, but not AHI or other sleep variables. A limitation of this study is that PSG was performed in the homes of the participants and, thus, was often of lower quality and shorter duration than in the laboratory.

Altogether, evidence supports an adverse impact of OSA on glycemic control in patients with type 2 diabetes. As differences in A1c levels among patients with different degrees of severity of OSA are comparable to the effect size of the most powerful combinations of available diabetes medications, multiple studies have attempted to determine whether OSA treatment with CPAP in patients with diabetes improves glycemic control, as discussed later in this chapter.

### Obstructive Sleep Apnea and Diabetes Complications

The development of microvascular complications of diabetes is associated with poor long-term glycemic control and increased health care costs. Because OSA is associated with activation of the sympathetic nervous system and of inflammatory processes, as well as oxidative stress, it is likely that OSA contributes to the development and/or progression of these complications irrespective of strategies to optimize diabetes control. Although the details are beyond the scope of this chapter, there is evidence that type 2 diabetes patients with OSA may suffer more complications, including peripheral neuropathy, retinopathy, and nephropathy (142,143,144), than those without OSA, with the degree of oxygen desaturation being an independent predictor in some studies (142,143). This field is a subject of ongoing research to establish whether OSA is an independent predictor of diabetes complications and whether OSA treatment delays the development or decreases the severity of microvascular complications.

### REM-Related Obstructive Sleep Apnea

The reduction in pharyngeal muscle activity that normally occurs during REM sleep is associated with more prolonged obstructive events and more severe oxygen desaturation in OSA patients (145). In some patients, the respiratory events occur predominantly during REM sleep. This phenomenon has been termed “REM-related OSA” and is prevalent in 10%–36% of OSA patients (146). Compared to NREM sleep, apneas and hypopneas during REM sleep are associated with higher sympathetic nervous system activation and greater degrees of hypoxemia (147). REM-related OSA may lead to greater cardiometabolic derangements and more adverse health consequences (146). This hypothesis was addressed for the first time in a cross-sectional study involving laboratory PSG in 115 participants with type 2 diabetes. Higher REM AHI and REM microarousal index were significantly correlated with higher A1c levels, supporting the significance of REM-related OSA for glucose metabolism (148). In contrast, associations between NREM AHI or NREM microarousal index and A1c were nonsignificant. An important implication of this study is that metabolic benefits of CPAP treatment of OSA may not be achieved with CPAP use of only 3–5 hours per night.

### Effects of Continuous Positive Airway Pressure Treatment on Glucose Metabolism and Diabetes Control

Given the large body of relatively consistent data relating OSA to abnormalities in glucose metabolism, it is somewhat surprising to find that studies on the effects of treatment with CPAP therapy on glucose metabolism in OSA have produced equivocal results (149,150,151). While some investigators have demonstrated a favorable effect of CPAP therapy on glucose metabolism (152), others have found no effect. Among the nine randomized controlled trials (RCTs) comparing active CPAP to sham-CPAP with treatment duration between 1 week and 3 months and device use of 2.8–6.2 hours per night, six found that active CPAP did not improve fasting glucose levels or insulin sensitivity (153,154,155,156,157), one observed an improvement of insulin sensitivity at 24 weeks (nonrandomized part of the study) but not at 12 weeks during randomization (158), and two reported an improvement in insulin sensitivity, mainly in obese patients or those with severe OSA (159,160). In a study focusing only on patients with relatively well-controlled diabetes (A1c 6.5%–8.5% [48–69 mmol/mol]), CPAP treatment did not result in significant changes in A1c levels (161).

Five meta-analyses have tried to summarize the impact of CPAP treatment on markers of glucose metabolism (162,163,164,165,166). The inclusion criteria of these meta-analyses varied between including only studies with inactive control or sham CPAP, including both observational studies and RCTs, or including only the studies that utilized A1c as a part of the outcome measures. Therefore, these five meta-analyses included different studies with some overlap. Hecht et al. reported no effect of CPAP treatment on insulin, HOMA, or A1c levels from six studies utilizing inactive control or sham CPAP (total 296 participants) (164). Iftikhar et al. reported no effects on A1c from nine studies (both observational and RCTs) involving 151 participants (162). This conclusion is in agreement with the study by Chen et al. that found no improvement in A1c levels, although the index of insulin resistance improved significantly (165). In nondiabetic subjects, there seems to be an improvement of insulin resistance after CPAP therapy. Yang et al. found an improvement in HOMA-IR with a mean difference of −0.55 (95% CI −0.91 to −0.20) in nondiabetic subjects with moderate to severe OSA (from nine studies, both observational and RCTs, totaling 248 subjects) but no differences in fasting glucose levels in 39 diabetic participants from two studies (163). Similar results were found in the analysis by Iftikhar et al. (166).

The inconsistency of results in the published literature is most likely due to a number of methodologic limitations, such as small sample sizes, inadequate consideration for the confounding effects of obesity, lack of data on CPAP compliance, or suboptimal CPAP compliance. As mentioned earlier, there is evidence that the adverse impact of untreated OSA on glycemic control in diabetes may be primarily caused by obstructive events occurring during REM, rather than NREM, sleep (148). CPAP use of 3–5 hours per night only treats a small portion of REM-related events and could be the reason why several RCTs of CPAP in diabetic patients have failed to observe a beneficial effect on glycemic control. Alternatively, it is plausible that the metabolic effects of OSA are irreversible, particularly if recurrent exposure to intermittent hypoxemia and sleep fragmentation causes irreparable changes in insulin sensitivity, insulin secretion, or both. In light of the limited data, it is indeed premature to infer whether CPAP therapy in OSA does or does not improve glucose metabolism. Ongoing research efforts in the form of randomized clinical trials will hopefully help determine whether CPAP therapy has favorable effects on glucose metabolism among patients with OSA. Of note, a RCT examining the impact of 8 hours of nightly CPAP in the laboratory on glucose tolerance in individuals with prediabetes reported positive findings (167).

### Mechanistic Links Between Obstructive Sleep Apnea and Metabolic Dysfunction

If the link between OSA and abnormalities in glucose metabolism is eventually proven to be causal, what are the potential mechanisms that underlie the association? Most likely, alterations in glucose homeostasis induced by OSA are mediated by a complex set of interactive mechanisms that are triggered by the cyclical hypoxemia and recurrent arousals from sleep (Figure 25.5) (168). In the sections that follow, physiological systems that may play an important role in mediating the effects of OSA on glucose metabolism are highlighted. Particular focus is given to the sympathetic nervous system, the hypothalamic-pituitary-adrenal (HPA) axis, formation of reactive oxygen species (ROS), and low-grade systemic inflammation. It is important to recognize that for each physiological system influenced by OSA, intermittent hypoxemia and sleep fragmentation may perturb the system independently or synergistically.

FIGURE 25.5 Putative Mechanisms Linking Sleep Apnea to Type 2 Diabetes

Flow chart showing possible pathways in which obstructive sleep apnea leads to insulin resistance, glucose intolerance, and ultimately type 2 diabetes

SOURCE: Reference 168, copyright © 2015 Elsevier, reprinted with permission

#### Role for the Sympathetic Nervous System

Compared to normal subjects, patients with OSA exhibit higher levels of sympathetic nervous system activity not just during sleep, but also during wakefulness (169). The decrease in oxyhemoglobin saturation and the concurrent increase in carbon dioxide with each disordered breathing event elicit a chemoreflex-mediated surge in sympathetic activity (170,171). Observational and experimental studies have demonstrated that even brief arousals from sleep can lead to a surge in sympathetic activity (172,173). Thus, intermittent hypoxemia and recurrent arousals from sleep can shift autonomic balance in patients with OSA. Although the exact mechanisms through which sympathetic activation affects insulin sensitivity are not well defined, there is little doubt that it has a central role in the regulation of glucose and fat metabolism (174). Catecholamines reduce insulin sensitivity and insulin-mediated glucose uptake (175). Administration of epinephrine in normal subjects can decrease insulin-mediated glycogenesis, increase glycolysis, and dampen the ability of glucose to stimulate its own disposal (176,177). Higher levels of sympathetic activity have lipolytic effects through signaling pathways that activate hormone-sensitive lipase, which can mobilize nonesterified fatty acids (178). An abrupt increase in circulating free fatty acids can worsen insulin sensitivity, while a decrease can improve insulin sensitivity, hyperinsulinemia, and glucose tolerance (179,180). In addition to the above effects, activation of the sympathetic nervous system can lead to systemic vasoconstriction, which can also affect glucose metabolism. A decrease in vascular lumen size in skeletal muscle from vasoconstriction shunts glucose and insulin to less metabolically active areas of skeletal muscle (181) and, thus, decreases overall glucose uptake (182). Sympathetic activation can also alter skeletal muscle morphology to a more insulin resistant type (183), inhibit insulin signaling, and decrease insulin-mediated glucose uptake by adipocytes (184). Thus, there is sufficient basis to speculate that an increase in sympathetic nervous system activity due to recurrent intermittent hypoxemia and sleep fragmentation plays a central role in altering glucose metabolism in sleep apnea.

#### Role of the Hypothalamic-Pituitary-Adrenal Axis

Recurrent intermittent hypoxemia and arousals in OSA could alter glucose metabolism by modulating the function of the HPA axis. Specifically, a stress-related increase in HPA activity and cortisol secretion could lead to insulin resistance and hyperglycemia. Observational data from studies of high altitude or of hypobaric conditions indicate that hypoxia modifies the diurnal pattern of the HPA axis and increases circulating cortisol (185,186,187,188,189,190,191). Moreover, brief arousals or sustained awakenings from sleep can activate the HPA axis and can further augment corticotropic function (192,193). However, experimentally induced micro-arousals designed to selectively suppress SWS for three consecutive nights in healthy young adults had no significant impact on the 24-hour profile of cortisol levels, despite an overall sleep fragmentation in the range of that associated with moderate to severe OSA (41). A notable limitation in many of the available studies on HPA axis activity in OSA is that corticotropic function was assessed with a single measurement of serum cortisol. While convenient, isolated cortisol measurements cannot reveal diurnal changes or the temporal variability in cortisol secretion.

Characterizing HPA dysfunction in OSA has scientific and clinical relevance, as it would help clarify its putative role in mediating insulin resistance and glucose intolerance. It is well established that cortisol and other glucocorticoids interfere with glucose metabolism at several different levels (194,195). Cortisol increases hepatic gluconeogenesis and causes protein degradation. It also activates lipoprotein lipase, which mobilizes nonesterified fatty acids and can greatly diminish insulin sensitivity. Moreover, cortisol inhibits beta cell secretion of insulin and sequentially modifies multiple aspects of the insulin-mediated glucose transport system. In a small study of CPAP treatment of OSA in obese women with the polycystic ovary syndrome, there was a trend for reduced evening cortisol concentrations following CPAP (196). Given the myriad of adverse metabolic effects of HPA dysfunction, further research is needed to determine whether OSA affects HPA activity and, thus, alters glucose metabolism function.

#### Reactive Oxygen Species as a Causal Intermediate

Repetitive cycles of hypoxemia followed by re-oxygenation in OSA could increase ROS production similar to what has been observed with ischemia-reperfusion injury (197,198). Data indeed suggest that OSA is associated with higher concentrations of ROS that may, in turn, negatively influence glucose metabolism. Using study samples of modest size along with assessments before and after initiation of CPAP therapy, a number of studies have shown abnormalities in lipid peroxidation, higher isoprostane levels, and elevated markers of DNA oxidation in patients with OSA compared to normal subjects and a decline in these markers after treatment with CPAP (199,200,201,202,203). Moreover, antioxidant defenses may also be diminished in OSA (204,205). Finally, a number of in vitro studies have shown that apneic patients have increased adhesion molecule expression and production of ROS in leukocytes (206), an augmented release of neutrophil superoxide (207), and increased oxidized low-density lipoprotein (LDL) autoantibodies (208).

Excessive concentrations of ROS can be harmful particularly to the pancreatic beta cell given that this cell population is relatively low in antioxidant enzyme mechanisms, such as catalase, glutathione peroxidase, and superoxide dismutase (209). ROS formation is also accompanied by an inhibition of insulin-stimulated substrate uptake in insulin-sensitive tissues, such as muscle and adipose tissue (210,211,212). Moreover, several studies also suggest that pharmacological doses of the antioxidants vitamin E, vitamin C, and lipoic acid in healthy volunteers and diabetic patients may improve insulin sensitivity and metabolic control (213,214,215,216). While mechanisms underlying the effects of an altered redox state on insulin sensitivity require further elucidation, several converging lines of evidence, including clinical and experimental data, indicate that oxidative stress is a causative factor. Thus, OSA-associated increase in free radical generation could represent a causal component for the development of insulin resistance.

#### Importance of Systemic Inflammation and Adipocytokines

Low-grade systemic inflammation may be yet another mechanism relating OSA to disorders of glucose metabolism. Compared to normal subjects, patients with OSA have higher levels of circulating adhesion molecules (217,218,219,220,221,222) and inflammatory cytokines, including IL-6 and TNF-alpha, which decrease with CPAP therapy (223,224,225,226). Studies examining specific leukocyte populations also reveal that OSA patients exhibit monocyte and lymphocyte activation, which improve with CPAP therapy (227,228,229). In normal subjects, hypoxia increases circulating leukocyte concentration and alters the functional characteristics of lymphocytes (230,231,232). Sympathetic hyperactivity in sleep apnea may also influence the innate immune response given that adrenergic stimulation enhances macrophage and lymphocyte activity and alters their proliferation, circulation, and cytokine production (233,234). A concern in invoking systemic inflammation as an intermediate between OSA and metabolic dysfunction is the confounding effects of obesity. Adipose tissue can increase systemic inflammation, as visceral adiposity has an enhanced capacity to produce numerous cytokines, including IL-6 and TNF-alpha. However, it appears that even after considering the effects of BMI and measures of visceral obesity, sleep apnea severity is independently correlated with the degree of inflammatory burden (235). Thus, low-grade systemic inflammation could potentially mediate the adverse metabolic effects of OSA.

In addition to the systemic inflammation, adipocyte-derived factors, such as leptin, adiponectin, and resistin, may play a role in the genesis of sleep apnea-related abnormalities in glucose metabolism. Leptin regulates hunger and weight gain by increasing anorexigenic and decreasing orexigenic neuropeptides in the hypothalamus (236). Peripherally, leptin appears to be involved in governing glucose homeostasis (237,238). A growing body of literature shows that patients with sleep apnea have higher leptin levels (239,240,241,242,243,244,245), which decrease with CPAP therapy independent of any changes in body weight (246,247,248,249). Moreover, exposure to hypoxic conditions increases leptin levels in normal subjects (250). Thus, higher leptin levels in OSA could certainly alter glucose metabolism. Adiponectin has endogenous insulin-sensitizing properties. Adiponectin is lower in patients with sleep apnea than in normal subjects, and circulating levels appear to correlate with the nadir in oxygen saturation (251,252,253,254,255,256,257). Resistin is another adipocytokine that inhibits insulin action and may have a role in the pathogenesis of type 2 diabetes (258,259). At present, there are limited data on whether resistin levels differ between patients with OSA and control subjects (251,260,261). Clearly, additional work is needed to determine whether adiponectin and resistin are affected by intermittent hypoxemia and recurrent arousals and whether these adipocytokines could be involved in causing metabolic dysfunction in OSA.

### Impact of Type 2 Diabetes on Breathing Disorders During Sleep

While much of the discussion has been focused on the consideration that OSA contributes to metabolic dysfunction, there is also the possibility of reverse causation. That is, once hyperglycemia and type 2 diabetes develop, can these then contribute to the incidence or worsening of OSA? Cross-sectional studies demonstrating a high prevalence of OSA in type 2 diabetes do not provide evidence for a direction of causality.

Data on the occurrence and temporal progression of OSA in diabetic individuals are lacking, as are studies exploring the possibility that type 2 diabetes could worsen OSA severity (262,263,264,265,266). Experimental data from animal models show that insulin resistance is associated with reduced ventilatory response that can be enhanced with insulin treatment (267). Whether such abnormalities in ventilatory control have downstream consequences and increase human predisposition to apneas and hypopneas during sleep is not known. Ongoing research efforts based on longitudinal studies will hopefully clarify whether progression of OSA differs between diabetic and nondiabetic subjects and is affected by glycemic control or the type of pharmacological treatment of diabetes.

Type 2 diabetes may also promote the expression of central sleep apnea. Using data from the community-based Sleep Heart Health Study, Resnick et al. (135) showed that participants with type 2 diabetes had a higher prevalence of Cheyne-Stokes or periodic breathing and central respiratory events during sleep than those without type 2 diabetes. In this cross-sectional analysis, the higher prevalence of periodic breathing in diabetic versus nondiabetic individuals (OR 1.74) persisted even after accounting for multiple covariates, including age, sex, BMI, and prevalent cardiovascular disease. It is possible that diabetes-associated autonomic dysfunction may lead to instability of the respiratory control system via enhanced central chemoreceptor-mediated gain, as well as cardiac impairments with prolonged circulatory time. Evidence supporting the notion that diabetic individuals with autonomic neuropathy may have a heightened response to hypercapnia has been previously described (268). Coupled with numerous clinical case series (269,270,271), the available research suggests that central sleep-disordered breathing is prevalent in type 2 diabetes, particularly if there is concurrent evidence of autonomic dysfunction.

## Sleep Disturbances During Pregnancy: Relationship With Glucose Metabolism and Gestational Diabetes

Sleep alterations are common during pregnancy due to hormonal and physical changes. Progesterone has sedative effects and can stimulate respiratory drive, while estrogen increases hyperemia, mucosal edema, and upper airway resistance, resulting in nasal stuffiness and snoring (272). Upward displacement of the diaphragm may cause a reduction in functional residual volume of the lungs and, therefore, oxygen reserve. Nausea, vomiting, frequent urination, and backache can decrease sleep efficiency and increase nocturnal awakenings.

During the first trimester, sleepiness is common, and women report an increase in sleep duration of approximately 0.7 hours (273). However, sleep efficiency and percentage of SWS decrease significantly (274). Sleep duration decreases in the late second trimester (274), although there is an observed increase in percentage of SWS (275). During the third trimester, a majority of women report sleep disturbances. There is a decrease in percentage of SWS and REM sleep (272) with an increase in time spent in light NREM sleep (stage N1) (276). Wake time after sleep onset increases, but total sleep time approximates the prepregnancy state (274). At this stage of pregnancy, a majority of women report taking daytime naps (277). Snoring is quite common, as two large studies, including in total more than 2,700 pregnant women, revealed that about one-third of participants reported snoring, with 25% reporting pregnancy-onset snoring (278,279). Symptoms of OSA increased during pregnancy in a prospective study, especially in women whose BMI exceeded 25 kg/m^2^ (280).

Gestational diabetes mellitus affects 2%–25% of pregnant women and is associated with adverse maternal-fetal outcomes, as discussed in Chapter 4 Gestational Diabetes. An increased risk for gestational diabetes or hyperglycemia is associated with sleep disturbances, including OSA and snoring, short sleep duration, and increased daytime sleepiness. A review of the literature found 15 studies that investigated sleep and glucose intolerance in pregnancy: eight using questionnaires, six using objective sleep measurements, and one using both methods (Table 25.11) (278,279,281,282,283,284,285,286,287,288,289,290,291,292,293). Seven studies assessed sleep duration (five by self-report, one by combined self-report and PSG, and one by actigraphy) (281,282,284,286,289,290,293). Of these seven studies, four found a significant association between short sleep duration and increased risk for gestational diabetes/hyperglycemia (281,282,284,290). Twelve studies assessed symptoms of OSA or a diagnosis of OSA (278,279,281,282,283,284,287,288,289,291,292,293). Of the eight studies using questionnaires, five found significant associations between OSA symptoms and gestational diabetes or maternal hyperglycemia (279,281,282,284,289). Among the six studies using objective measurements (five used PSG and one used portable home monitoring) (287,288,289,291,292,293), four found a significant association between OSA and increased gestational diabetes/hyperglycemia risks (287,288,291,292). A meta-analysis included nine of these studies (total 9,795 participants) and found a significant association between OSA and gestational diabetes, with an odds ratio of 2.18 (95% CI 1.59–2.99) (294). When considering only studies including BMI as a covariate, the adjusted odds ratio was 3.06 (95% CI 1.89–4.96). One study found an association between severe daytime sleepiness and gestational diabetes, although the number of women with severe daytime sleepiness was small (285). In addition, increased daytime napping was found to be associated with maternal hyperglycemia in one study (289). The mechanisms by which sleep disturbances increase the risk for gestational diabetes are likely to overlap those linking sleep disturbances and metabolic alterations in nonpregnant populations but have not been studied specifically in pregnancy.

Short sleep, snoring, and OSA in pregnancy have been linked to other adverse maternal and fetal outcomes, including an increased risk of preeclampsia, gestational hypertension (GHTN), preterm birth, and unplanned caesarean delivery (278,279,288,295,296,297). A meta-analysis revealed an association between sleep-disordered breathing and GHTN, with an odds ratio of 2.34 (95% CI 1.60–3.03), as well as with low birth weight, with an odds ratio of 1.39 (95% CI 1.14–1.65) (298). Oxidative stress, release of proinflammatory cytokines, increased sympathetic activation, peripheral vasoconstriction, and endothelial dysfunction resulting from sleep disturbances are all likely to contribute to these complications (299).

Treatment with CPAP has been shown to be safe during pregnancy and to improve blood pressure control and pregnancy outcomes in women with hypertension and chronic snoring (300). The question of whether treating OSA during pregnancy improves glucose metabolism is crucial as maternal glycemia affects fetal health, but it has not yet been addressed.

TABLE 25.11 Studies Investigating the Association Between Sleep in Pregnancy and Gestational Diabetes or Hyperglycemia

YEARS (REF.) | SAMPLE SIZE | TIME OF ASSESSMENT | ASSESSMENT | OUTCOMES OF INTEREST^*^ | RESULTS
Studies utilizing questionnaires
2003–2006 (281) | 1,290 | Early pregnancy | Sleep duration Snoring | Gestational diabetes | Sleeping ≤4 h was associated with increased risk of gestational diabetes compared to sleeping 9 h (RR 5.56 [95% CI 1.31–23.69], with RR 3.23 [95% CI 0.34–30.41] for lean and RR 9.83 [95% CI 1.12–86.32] for overweight women), adjusting for age and race/ethnicity.; Women who snored “most or all of the time” had increased risk of gestational diabetes compared to those who did not snore (RR 1.86 [95% CI 0.88–3.94], with RR 6.9 [95% CI 2.87–16.2] for overweight women who snored).
NR (279) | 1,000 | Immediate postpartum period | Multivariable Apnea Prediction Index | Gestational diabetes | SDB symptoms were associated with gestational diabetes, OR 2.1 (95% CI 1.3–3.4), adjusting for age, BMI at delivery, multiple pregnancies, and current smoking.
2007–2008 (282) | 189 | Early pregnancy (6–20 weeks) and third trimester | Sleep duration Snoring | Gestational diabetes 1-h glucose values from 50 g OGTT | Women sleeping <7 h had higher glucose values and higher incidence of gestational diabetes, OR 11.7 (95% CI 1.2–114.5) than those who slept ≥7 h adjusting for age, race/ethnicity, BMI, and frequent snoring.; Women who snored ≥3 times/week had higher glucose values and higher incidence of gestational diabetes, OR 6.9 (95% CI 1.4–33.9), adjusting for age, race/ethnicity, BMI, and sleeping <7 h.
NR (283) | 465 | During pregnancy or admission for labor | Berlin Questionnaire | Gestational diabetes | More women with positive Berlin Questionnaire had gestational diabetes, but not after adjusting for BMI and maternal medical disorders.
2008–2010 (284) | 169 | Second trimester (26 weeks) | Pittsburgh Sleep Quality Index, Berlin Questionnaire, Epworth Sleepiness Scale | Gestational diabetes 1-h glucose values from 50 g OGTT | Each hour of reduced sleep time was associated with 4% increase in glucose levels.; Increased OSA risk was associated with gestational diabetes, OR 3.0 (95% CI 1.2–7.4).; Sleeping <7 h was associated with gestational diabetes, OR 2.4 (95% CI 1.0–5.9).; Combination of increased SDB risk and sleeping <7 h was associated with gestational diabetes, OR 3.4 (95% CI 1.3–8.7).; Frequent snoring (>3–4 days/week) was associated with gestational diabetes, OR 3.4 (95% CI 1.3–8.8).
2007–2010 (278) | 1,719 | Third trimester | Snoring | Gestational diabetes | No association between chronic snoring (3–4 times/week) or pregnancy-onset snoring with gestational diabetes.
2006–2008 (285) | 1,000 | Immediate postpartum period | Epworth Sleepiness Scale | Gestational diabetes | No association with gestational diabetes in those with score >10.; Significant association with gestational diabetes was found in those with score >16 after adjusting for age, BMI at delivery, and current smoking. The authors cautioned that the number of women with score >16 was small.
NR (286) | 1,211 | Second to third trimester | Self-reported sleep duration | Maternal hyperglycemia defined as 1-h glucose value ≥140 mg/dL after 50 g OGTT | No differences in glucose values were found between short sleepers (≤6 h/night), normal sleepers (7–9 h/night), or long sleepers (≥10 h/night).
Studies utilizing objective measures of sleep
2000–2009 (287) | 143 | PSG: 46% before and 54% after delivery | PSG; mild (AHI 5–14.9) and moderate to severe OSA (AHI ≥15) | Gestational diabetes (as a part of adverse pregnancy outcomes) | Thirty-four women with mild and 26 with moderate to severe OSA. Six women had gestational diabetes.; None of the women without OSA had gestational diabetes, while 5.9% of those with mild OSA and 11.5% of those with moderate to severe OSA had gestational diabetes (p=0.004).
2005 (288) | 791 with OSA and 3,955 age-matched women presumed without OSA | Women with OSA had PSG within 1 year prior to index deliveries. Matched controls did not have PSG. | PSG; diagnosis of OSA | Gestational diabetes | One hundred and sixty-seven women were diagnosed with gestational diabetes.; OSA was significantly associated with gestational diabetes, OR 1.63 (95% CI 1.07–2.48) after adjusting for education, marital status, gestational hypertension, anemia, coronary heart disease, hyperlipidemia, obesity, geographic region, paternal age, infant’s sex, and parity.
NR (289) | 104 | First trimester, 83 had repeated PSG in third trimester | PSG Pittsburgh Sleep Quality Index, Multivariable Apnea Prediction Index | Maternal hyperglycemia defined as 1-h glucose value ≥135 mg/dL after 50 g OGTT | Eleven women had hyperglycemia.; Self-reported loud snoring, snorting/gasping, and apneas were associated with maternal hyperglycemia, OR 3.37 (95% CI 1.44–8.32) after adjusting for age, race, neck circumference, and shift work.; Self-reported nap duration was associated with hyperglycemia, OR 1.64 (95% CI 1.00–2.68) after adjusting for age, race, and neck circumference.; First trimester AHI, self-reported sleep duration, sleep duration and efficiency by PSG were not associated with hyperglycemia.
2009–2010 (290) | 76 | 21 weeks of gestation | Actigraphy for 6 days; sleep duration | 1-h glucose after 50 g OGTT | Each hour of reduced sleep time was associated with 8.2 mg/dL increase in glucose levels.; Shorter night time sleep was associated with hyperglycemia (glucose ≥130 mg/dL) after adjusting for age and BMI, OR 0.2.
NR (291) | 75 (high-risk group for preeclampsia) | 17 weeks of gestation | Portable monitor (WPAT200); diagnosis of OSA | Gestational diabetes | OSA was significantly associated with gestational diabetes, OR 3.7 (95% CI 1.1–13.3) after adjusting for maternal age, BMI, and history of chronic hypertension.
2009–2012 (292) | 45 (15 GDM, 15 pregnant NGT, and 15 nonpregnant NGT; matched for age and ethnicity) | Late second to early third trimester in pregnant women | PSG; diagnosis of OSA (AHI ≥5) | Risk of OSA in women with gestational diabetes | Eleven women with gestational diabetes (73%) had OSA.; Gestational diabetes was significantly associated with OSA, OR 6.6 (95% CI 1.15–37.96), after adjusting for prepregnancy BMI.; In NGT women, pregnancy was associated with higher AHI, microarousal index, and wake time after sleep onset.
Study utilizing questionnaire and objective measure of sleep
2010–2012 (293) | 52 (26 GDM and 26 NGT, BMI <35 kg/m^2^); matched by gestational age at PSG, age, and BMI | 24–32 weeks of gestation | PSG; diagnosis of OSA (AHI ≥5), self-reported sleep duration | Risk of OSA in women with gestational diabetes | No significant differences in OSA diagnosis between controls and participants with gestational diabetes, 20% versus 31%, respectively, prepregnancy BMI-adjusted OR 1.90 (95% CI 0.52–6.88).; No significant differences in AHI (control vs. gestational diabetes; mean 4.2 vs. 3.8), oxygen desaturation index, snoring, and flow limitation, self-reported sleep duration between the two groups.

Conversions for glucose values are provided in Diabetes in America Appendix 1 Conversions. AHI, apnea-hypopnea index; BMI, body mass index; CI, confidence interval; GDM, gestational diabetes mellitus; h, hour; NGT, normal glucose tolerance; NR, not reported; OGTT, oral glucose tolerance test; OR, odds ratio; OSA, obstructive sleep apnea; PSG, polysomnogram; RR, relative risk; SDB, sleep-disordered breathing.

* Many studies had other outcomes of interest, but only outcomes related to glucose metabolism are summarized in this table.

SOURCE: References are listed within the table.

## The Circadian System and Glucose Metabolism

The circadian system, controlled by the master circadian clock located in the suprachiasmatic nuclei (SCN) of the hypothalamus, plays a major role in regulating daily rhythms of sleep/wake cycle, feeding behavior, central and peripheral tissue metabolism, and hormonal secretions (301). The clock in the SCN is synchronized to the 24-hour day primarily by light signal via the retinohypothalamic tract. It then relays the information via hormonal and neuronal pathways to the rest of the brain and to peripheral organs, such as the heart, liver, adipose tissue, muscle, adrenals, and pancreas, which all possess “peripheral clocks,” leading to coordinated rhythms and behaviors (Figure 25.6) (2,302). The central clock mechanism consists of a transcription-translation negative feedback loop involving several core clock genes including Clock (circadian locomotor output cycles kaput), Bmal1 (brain and muscle Arnt-like protein-1), Per 1–3 (Period 1–3), and Cry 1–2 (Cryptochrome 1–2), as well as feedback signals from nutrient intake (303).

There is evidence that circadian disruption has detrimental effects on energy metabolism. It was first shown that Clock mutant mice shift their feeding and activity behavior to their normally inactive phase and develop obesity and the metabolic syndrome (hyperlipidemia, hepatic steatosis, hyperglycemia, and hypoinsulinemia) (304). Habitual sleep duration in this mutant animal is about 1 hour shorter than in the wild type animal, thus resulting in a condition of lifelong insufficient sleep (304). In another study, wild type mice exposed to dim light during their usual biological night were shown to shift their food intake into the inactive phase. This was associated with reduced glucose tolerance and a greater gain in body mass, suggesting that eating at an adverse circadian time may contribute to metabolic dysfunction (305).

In humans, living in modern industrialized societies with 24-hour access to light coupled with work/social obligations often leads to behaviors that are inappropriately timed relative to endogenous circadian rhythms. This mismatch in timing is termed “circadian misalignment.” Night shift work is an example of severe circadian misalignment, as workers are awake, active, and eating during their biological night and trying to sleep and fast during their biological day. In 2004, 14.8% of all workers in the United States had work schedules differing from a daytime schedule (306). This proportion was much higher for workers in service occupations, such as security (50.6%), and for health care professionals (38.3%). Shift work is associated with abnormal glucose metabolism, including IGT and diabetes. In a retrospective study of 6,413 participants in Japan followed for 9.9 years, two groups of rotating shift workers with slightly different schedules both had a significantly increased risk of developing IGT (defined as A1c ≥5.9% [≥41 mmol/mol]) with hazard ratios of 1.78 (95% CI 1.49–2.14) and 2.62 (95% CI 2.17–3.14) (307). In addition, longer duration of shift work, in a dose response fashion, was associated with a gradual increase in A1c levels over time in those without diabetes at baseline (308). Most cross-sectional studies, all outside the United States, have also found an association between shift work and prevalence of diabetes (Table 25.12).

FIGURE 25.6 Illustration of the Circadian System Regulation

SCN, suprachiasmatic nuclei.

Flow chart showing that sunlight affects the S C N, which in turn uses neural and hormonal signals to other organs in order to regulate the circadian rhythm

SOURCE: Reference 2, copyright © 2014 New York Academy of Sciences, reprinted with permission

To date, 11 of 12 prospective and retrospective cohort studies demonstrated that shift work was associated with an increased risk of developing diabetes (Table 25.13) (29,30,309,310,311,312,313,314,315,316,317,318). The largest study, the Nurses’ Health Study I and II, followed 177,184 participants for 18–20 years and found that those who worked rotating night shifts had increased hazard ratios for diabetes of 1.03–1.24, after adjusting for traditional diabetes risk factors, as well as BMI, with higher risk in those who had a longer duration of shift work compared to those reporting no shift work (314). The risk was estimated to be a 5% increase for every 5 years of shift work. Night shift work was found to be associated with incident diabetes in participants of the Black Women’s Health Study (2005–2013), with increasing risk according to the number of years night shift work was performed (HR 1.17, 95% CI 1.04–1.31, for 1–2 years; HR 1.23, 95% CI 1.06–1.41, for 3–9 years; and HR 1.42, 95% CI 1.19–1.70, for ≥10 years) (318).

There may be several reasons why shift workers are at higher risk for developing diabetes. Besides circadian misalignment, insufficient sleep and poor sleep quality, themselves associated with increased diabetes risk, are very common among shift workers. Compared to day workers, shift workers have higher rates of obesity and more unfavorable lifestyle factors, including physical inactivity, alcohol consumption, and habitual smoking (313,315,319). In addition, there is evidence for excessive total energy intake (319), although it is not consistent (320,321). Adjusting for adiposity and lifestyle factors attenuated the relationship between shift work and diabetes in some studies, but significant residual effects remained (312,313,314,315). One meta-analysis of cohort studies revealed that shift work was associated with incident diabetes with an odds ratio of 1.12 (95% CI 1.06–1.19) (322), while another found a pooled adjusted relative risk for rotating shift work of 1.15 (95% CI 1.06–1.25) (323). Although the magnitude of the increased risk associated with shift work was relatively modest when other risk factors were controlled, the findings suggest that shift work may compound the risk imparted by traditional risk factors.

TABLE 25.12 Cross-Sectional Studies Exploring Associations Between Shift Work and Diabetes

LOCATION, YEARS (REF.) | POPULATION | SAMPLE SIZE | SHIFT WORKER | OUTCOME | RESULTS
Japan, NR (428) | Male factory workers | 2,167 | Day workers versus three-shift workers | Diabetes, defined as glucose level after 50 g glucose challenge, >185 mg/dL at 1 hour and >150 mg/dL at 2 hours (Japanese Diabetic Society) | Prevalence of diabetes in three-shift workers was 2.1% versus 0.9% in day workers.
Japan, 1995–1998 (429) | Employees participating in yearly check-ups, age 30–59 years | 3,650 | Day shift versus any shift work | Hyperglycemia, defined as FPG ≥126 mg/dL | Shift work was associated with hyperglycemia in the age group 30–39 years, OR 6.75 (95% CI 1.31–56.1).; No association was found in the age groups 40–49 or 50–59 years.
Sweden, 1992–1998 (430) | Employees in paper and pulp manufacturing plants, age ≥20 years | 1,590 | Day shift versus three-shift work | Hyperglycemia, defined as FPG ≥126 mg/dL | Three-shift work was not associated with hyperglycemia.
Japan, 2009 (431) | Male employees participating in annual health check-ups | 475 | Day shift versus seasonal shift work versus continuous shift work | Diabetes, defined as FPG ≥126 mg/dL and A1c ≥6.5% | No association was found between shift work and diabetes in those age <45 years.; Among those age ≥45 years, the association between continuous shift work and diabetes was more pronounced, OR 2.24 (95% CI 0.71–7.06) versus OR 0.61 (95% CI 0.07–5.02) in seasonal workers.

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CI, confidence interval; FPG, fasting plasma glucose; NR, not reported; OR, odds ratio.

SOURCE: References are listed within the table.

TABLE 25.13 Cohort Studies of the Relationship Between Shift Work and Incident Diabetes or Impaired Glucose Tolerance

STUDY, YEAR (REF.) | POPULATION | SAMPLE SIZE | FOLLOW-UP (YEARS) | SHIFT WORK ASSESSMENT | DIABETES ASSESSMENT | RESULTS
Stockholm Diabetes Prevention Program, 1992–2006 (309) | Sweden, mean age 47.1 years | 5,432 | 8–10 | Shift work from questionnaire | OGTT, FPG ≥126 mg/dL or 2-hour glucose value ≥200 mg/dL | Shift work was not associated with diabetes after adjusting for multiple factors, OR 1.9 (95% CI 0.8–4.4) in women and OR 0.8 (95% CI 0.4–1.7) in men.
China, 2008–2010 (310) | Retired workers from Dongfeng Motor Corporation, mean age 63.6 years | 26,463 | Retrospective | Shift work from questionnaire | FPG ≥126 mg/dL or report of diabetes diagnosis or use of medication | Longer shift work (10–19 years and ≥20 years) was associated with diabetes, OR 1.10 (95% CI 1.00–1.22) and OR 1.16 (95% CI 1.06–1.27), respectively.
Pennsylvania, NR (311) | Retired shift workers, mean age 75.4 years | 1,111 | Retrospective | Work overlap 12:00–6:00 a.m., from questionnaire | Self-reported diabetes diagnosis | Longer exposures to shift work (8–14 years and >20 years) were associated with diabetes, OR 1.4 and OR 1.99, respectively.
Japan, 1993–2001 (312) | Male workers in a sash and zipper company, mean age 34.3 years | 2,860 | 8 | Dayshift, rotating two or three shift, from questionnaire | A1c ≥6.1% or report of diabetes diagnosis by physician | Two-shift work was associated with diabetes, RR 2.01 (95% CI 1.00–4.34). No association was found for three-shift workers.
Germany, 1995–2006 (313) | Workers from a chemical corporation, mean age 38.1 years | 31,346 | 11 | Rotating shift, from work registry | Diabetes diagnosis according to chart review | Shift work was associated with diabetes, HR 1.33 (95% CI 1.14–1.55).
Nurses’ Health Study I, 1988–2008 (314) | Age 42–67 years | 69,269 | 18–20 | Rotating night shift, from questionnaire | Self-reported diabetes diagnosis | Each 5 years of shift work was associated with diabetes, HR 1.05 (95% CI 1.02–1.07).
Nurses’ Health Study II, 1989–2007 (314) | Age 25–42 years | 107,915 | 18–20 | Rotating night shift, from questionnaire | Self-reported diabetes diagnosis | Each 5 years of shift work was associated with diabetes, HR 1.05 (95% CI 1.01–1.08).
Japan, 1991–2001 (315) | Workers from a Japanese steel company, mean age 36.1 years | 5,629 | 10 | Alternating shift from work registry | Self-reported diabetes diagnosis by physicians or A1c ≥6.0% | Alternate shift work was associated with diabetes, OR 1.35 (95% CI 1.05–1.75).
Japan, 2002–2010 (316) | Workers from a Japanese steel company, mean age 42.3 years | 8,423 | 8 | Daytime work or shift work from questionnaire | Self-reported diabetes diagnosis by physicians, A1c ≥6.1%, or use of medication | Shift work was associated with diabetes, HR 1.24 (95% CI 1.02–1.49).
Japan, 2003–2008 (29) | Government employees, age 35–55 years | 3,570 | 3–5 | Shift work from questionnaire | Having been prescribed diabetes medication and/or FPG ≥126 mg/dL | Shift work was not associated with diabetes, unadjusted RR 0.97 (95% CI 0.65–1.47).
Quebec Family Study, 1989–2001 (30) | Mean age 38.6 years | 276 | 6 | Questionnaire on sleep duration and shift work | Diabetes, defined as FPG ≥126 mg/dL or 2-hour glucose value ≥200 mg/dL after OGTT, or use of insulin or oral hypoglycemic agents; IGT, defined as 2-hour glucose value ≥140 mg/dL in those not meeting diabetes criteria | History of shift work was associated with diabetes/IGT, β 0.02, p=0.04.
Denmark, 2005–2012 (317) | Danish health care workers | 7,305 | 7 | Shift work from questionnaire | Being listed in the National Diabetes Registry^*^ | Shift work was borderline associated with diabetes, likelihood ratio 1.27 (95% CI 0.95–1.70).
Black Women’s Health Study, U.S., 2005–2013 (318) | Age 21–69 years | 28,041 | 8 | Night shift from questionnaire (00:00 hours to 08:00 hours) | Self-reported diabetes diagnosis, with a subgroup confirmed by contacting physicians | Night shift was associated with diabetes, HRs were 1.17 (95% CI 1.04–1.31) for 1–2 years of night-shift work, 1.23 (95% CI 1.06–1.41) for 3–9 years, and 1.42 (95% CI 1.19–1.70) for ≥10 years.; HR for those who ever worked night shift was 1.12 (95% CI 1.01–1.23).

Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CI, confidence interval; FPG, fasting plasma glucose; HR, hazard ratio; IGT, impaired glucose tolerance; NR, not reported; OGTT, oral glucose tolerance test; OR, odds ratio; RR, relative risk.

* Criteria for being listed in the National Diabetes Registry: 1. receive a diagnosis of diabetes; 2. receive diabetes-related chiropody care; 3. have blood glucose measured five times in a calendar year; 4. have at least two annual blood glucose measurements over a period of 5 consecutive years; 5. purchase prescribed oral antidiabetic medication; 6. purchase prescribed insulin.

SOURCE: References are listed within the table.

Human experiments in controlled laboratory settings have provided insights into metabolic alterations under experimentally induced circadian misalignment. Ten healthy adults underwent a 10-day laboratory protocol that involved sleeping and eating on a 28-hour “day.” Circadian misalignment, when the participants ate and slept 12 hours out of phase from their habitual times, was associated with a 6% increase in glucose levels despite a 22% increase in insulin concentration. Further, leptin levels decreased. Three subjects had postprandial glucose responses in a prediabetic range (324). Another carefully conducted experiment combined sleep restriction with circadian disruption and involved 24 participants studied for more than 5 weeks in a controlled laboratory setting (325). After 3 weeks of sleep restriction to 5.6 hours per day sleep and recurring 28-hour “days,” fasting and postprandial glucose levels were increased by 8% and 14%, respectively. These changes were apparently caused by decreased beta cell function, as plasma insulin decreased by 12% during fasting and 27% after meals. The metabolic derangements returned to baseline levels after 9 days of sleep recovery. There is also evidence that adverse effects of circadian misalignment on glucose metabolism can occur independently of sleep loss. Experimental circadian misalignment with sleep restriction (5 hours) in healthy volunteers led to a reduction in insulin sensitivity and an increase in inflammatory markers, compared to sleep-restricted participants who maintained regular nocturnal bedtimes, despite nearly identical sleep duration between the two groups (13). In addition, a 6-day simulated shift work experiment in 14 healthy adults found reduced total daily energy expenditure during nightshift schedules, as well as in response to dinner consumed late at night (326). Lastly, an experimental study designed to distinguish the effects of the behavioral cycles (sleep/wake, fasting/feeding, and activity schedules), the endogenous circadian system, and circadian disruption on glucose and lipid metabolisms was conducted in 14 volunteers (327). The protocol involved two 8-day crossover studies when the behavioral cycles were aligned or misaligned (12-hour shift) with endogenous circadian rhythms. Glucose tolerance was assessed at 8 a.m. and 8 p.m. in response to an identical mixed meal. Postprandial glucose levels were 17% higher in the biological evening than in the morning, and the early phase postprandial insulin response was 27% lower in the biological evening, indicative of insufficient beta cell response. This endogenous circadian effect was much larger than that of the behavioral cycle effect. In addition, circadian misalignment (12-hour behavioral cycle inversion) increased postprandial glucose levels by 6% despite a 14% higher late phase postprandial insulin response, suggesting reduced insulin sensitivity during misalignment. This study reveals potential mechanisms by which shift workers who are awake and eating during their biological night may increase the risk of weight gain, obesity, and diabetes (326).

In patients with established diabetes, shift work may be associated with poor glycemic control, but the data are scarce. In a small study of 32 patients with diabetes, there were no differences in glycemic control between those working day and shift schedules (328). However, after being moved to a rotating shift pattern, insulin-treated patients had significant deterioration in their glycemic control after 6 months. In another study of 120 day and 120 shift workers in Thailand, fasting glucose levels were significantly lower in day compared to shift workers (329). A larger study was conducted in 296 type 1 diabetes patients in the United Kingdom, 23% of whom performed shift work (330). A1c levels were significantly higher in shift compared to day workers with a mean 9.02% (75 mmol/mol) versus 8.35% (68 mmol/mol) (p<0.01). As the world now requires a 24-hour workforce, while the number of diabetes patients and the cost of care are increasing, attention should be paid to the metabolic health of shift workers. Pharmacotherapy improves alertness and sleep quality in those with shift work disorders, including melatonin (to improve daytime sleep) and modafinil or armodafinil (wake-promoting agents) (331). It is unknown whether these agents also help improve glucose metabolism in shift workers, but a placebo-controlled study of the metabolic impact of 1 week of sleep restriction found no beneficial effect of modafinil (12). Interestingly, a study in 43 workers on different shift schedules found that those with fast clockwise direction of shift work had lower fasting glucose levels and HOMA index than those with slow counterclockwise rotation and day workers (332). The study is limited by the small sample size, and the results need to be confirmed in a larger study.

Many individuals in modern society experience a form of mild circadian misalignment, especially during the work or school week, as they follow social rhythms imposed by professional obligations, school schedules, family, and other commitments rather than their own biological rhythms (333). The degree of misalignment is dependent on the individual’s “chronotype” (333). Chronotype is a construct that captures an individual’s preference for being a “morning” or “evening” person. Late chronotype is typically associated with a greater degree of misalignment between social rhythms and the circadian clock (333). Chronotype can be evaluated in several ways. In 1976, Horne and Ostberg developed the Morningness-Eveningness questionnaire to categorize respondents into five types (definitely morning, moderately morning, neither morning nor evening, moderately evening, and definitely evening) (334). These chronotypes correlate with the participants’ circadian timing of core body temperature. The core body temperature minimum is a classic phase marker and usually occurs during the second half of the habitual sleep period (334). Subsequently, Roenneberg et al. proposed the mid-sleep time on free days (MSF) as a metric of chronotype. MSF is derived from mid-sleep time (midpoint between sleep start and wake time) on weekend nights with further correction for calculated sleep debt, with the assumption that sleep timing on days when unconstrained by the social clock would more accurately reflect the underlying phase of the circadian system (335,336). A large cross-sectional study in Finland involving 4,589 participants found that those who were evening types had an odds ratio of 2.5 (95% CI 1.5–4.4) for type 2 diabetes compared to morning types. This association was independent of sleep duration and sleep sufficiency (337). Two separate cohorts (1,244 and 483 participants, respectively) provided similar findings, where eveningness was associated with increased risk of the metabolic syndrome (OR 1.4 and OR 2.2, respectively) (338,339) and diabetes (OR 2.0) (339). In addition, several genetic studies have shown that individuals carrying specific variants of the canonical circadian genes Clock and Bmal-1 had evening preference, resistance to weight loss, the metabolic syndrome, and susceptibility to type 2 diabetes (340,341,342).

Furthermore, evening chronotype in nondiabetic individuals was found to be associated with unfavorable cardiometabolic profiles (343). A study involving 119 obese short sleepers (≤6.5 hours per night) revealed that eveningness was associated with eating later and larger food portion size, an increase in BMI, and lower high-density lipoprotein (HDL) cholesterol level. Evening types were also found to have more sleep apnea and higher stress hormones. These results are suggestive of a higher risk of cardiovascular disease in this population.

The first study to address the contribution of chronotype on glycemic control in patients with type 2 diabetes involved comprehensive questionnaires to assess sleep and eating habits in 194 non-shift worker participants who all had an established diagnosis of diabetes (344).

After adjusting for age, sex, race, BMI, insulin use, depressed mood, diabetic complications, and perceived sleep debt, chronotype, as assessed by MSF, was significantly associated with glycemic control (Figure 25.7). The difference in median A1c between participants in the 4th quartile of MSF compared to the 1st quartile was approximately 1.3%, a remarkably strong effect size. Besides having significant later bedtime/wake time and poorer glycemic control, participants with later chronotype were more depressed, had a higher BMI, and were significantly more likely to require insulin. This finding suggested that patients with type 2 diabetes who have a late chronotype may be more hypoinsulinemic, consistent with the findings in the Clock mutant mice. Subsequently, two studies in Japanese type 2 diabetes patients (total 826 participants) found that more evening preference as assessed by questionnaire was associated with higher A1c and lower HDL cholesterol levels, as well as poorer sleep quality (345,346).

Another neurohormone that plays an important role in circadian regulation is melatonin, secreted by the pineal gland. Its secretion is modulated by the light-dark cycle via the retinohypothalamic tract and the SCN and by the sympathetic nervous system (347). Melatonin is released during the biological night and inhibited by light exposure. Melatonin secretion follows a diurnal pattern with low levels during the day, an abrupt increase 1–2 hours before habitual bedtime, high levels throughout the night, and a progressive decrease initiated prior to habitual wake-up time (348,349). Melatonin exerts its effects through membrane receptors belonging to the class of G-protein coupled receptors (350). In mammals, there are two receptor isoforms: MT1 and MT2 (found in the brain, SCN, retina, and peripheral tissues) (351). Melatonin can entrain circadian rhythms due to the presence of MT1 and MT2 receptors in the SCN (352). In addition, both isoforms of melatonin receptors are found in the pancreatic beta cells and alpha cells (350), and melatonin has been shown to modulate insulin secretion through rather complex cascades involving several secondary messengers and possibly through alpha cell stimulation (350,353). Therefore, melatonin may act as a mediator between the central circadian regulation and peripheral metabolism, as well as an internal signal synchronizing the central circadian clock and clocks in peripheral tissues. A review has suggested that the increased duration of exposure to light that is common in modern society may inhibit melatonin release and disrupt seasonal cycles. The authors further suggest that these factors could be involved in causing metabolic disturbances (354).

FIGURE 25.7 Median A1c Levels Across Quartiles of Mid-Sleep Time on Free Days

Those with later chronotypes had significantly higher A1c levels and later bedtimes/wake times than those with earlier chronotypes. Error bars represent interquartile ranges. Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; MSF, mid-sleep time on free days; Q, quartile.

Bar chart showing a mean A1c of 7.0% in those with the earliest chronotype and increasing to 8.3% in those with the latest chronotype

SOURCE: Reference 344

Genetic studies have linked the gene encoding MT2, MTNR1B, to abnormal glucose metabolism and diabetes risk (355,356,357,358). In a study involving 19,605 Europeans, the MTNR1B intronic variant, rs10830963, was associated with a significantly increased risk of impaired fasting glucose with an odds ratio of 1.6 (355). In addition, analyses in subgroups of this population revealed an association of this genetic variant with increased type 2 diabetes risk with odds ratios of 1.19 (95% CI 1.08–1.32) (French case-control study) and 1.23 (95% CI 1.10–1.37) (Danish case-control study). This allele was associated with decreased insulin secretion after oral and intravenous glucose challenges. Another study in 1,276 healthy individuals of European ancestry revealed that this MTNR1B variant was associated with higher fasting glucose levels, decreased early insulin response, and decreased beta cell glucose sensitivity as evaluated by an oral glucose tolerance test (OGTT) and a euglycemic-hyperinsulinemic clamp (356). Because the effect of this allele on diabetes risk was modest, a large-scale exon resequencing was conducted in 7,632 Europeans, including 2,186 individuals with type 2 diabetes (359). This identified 40 nonsynonymous variants, including 36 very rare variants, which were associated with a much higher increased risk for type 2 diabetes (OR 3.31, 95% CI 1.78–6.18). Among the rare variants, those with partial or total loss of function (i.e., complete loss of melatonin binding and signaling capabilities), but not the neutral ones, significantly contributed to diabetes risk (OR 5.67, 95% CI 2.17–14.82).

A well-documented epidemiologic study demonstrated a link between low nocturnal melatonin secretion and development of diabetes (360). In this case-control study nested within the Nurses’ Health Study Cohort, 370 women who developed type 2 diabetes during a follow-up of 10–12 years were matched with 370 controls. Women with the lowest baseline urine secretion of 6-sulfatoxymelatonin, a major metabolite of melatonin, had an increased risk of subsequent diabetes development with an odds ratio of 2.17 (95% CI 1.18–3.98) compared to those with the highest levels, after adjusting for demographic factors, lifestyle habits, sleep duration, snoring, and biomarkers of inflammation and endothelial dysfunction. The authors postulated several mechanisms by which low melatonin may be associated with diabetes, including reduced sleep duration and sleep apnea, which are known to be associated with low melatonin levels (361,362) but could not be accurately captured by the study questionnaires.

Increasing melatonin level by exogenous supplementation in patients with diabetes was tested in a randomized, double blinded, cross-over study involving 36 type 2 diabetes patients with insomnia (363). Prolonged-release melatonin administration significantly improved sleep efficiency and reduced wake time after sleep onset as assessed by actigraphy at 3 weeks, but without changes in glucose levels. A1c improved significantly at 5 months during the open-labeled phase (−0.6% compared to baseline) without changes in C-peptide levels, but the magnitude of this improvement was not predicted by sleep improvements as assessed by actigraphy. The study was limited by the lack of assessment of the circadian system. Interestingly, an experimental study in 21 healthy women revealed that acute melatonin administration, both in the morning and evening, resulted in IGT as assessed by OGTT (364). Therefore, the role of melatonin in human glucose metabolism remains controversial.

Taken together, these human experimental studies, results from cross-sectional studies, and genetic data support the contribution of the circadian system and sleep timing in metabolic regulation. Prospective and interventional studies are required to evaluate the role of the circadian system in the development and severity of type 2 diabetes.

## Combined Effects of Multiple Disturbances of Sleep and/or Circadian Function on Glucose Metabolism

While there has been little systematic study of the combined effects of the presence of several subtypes of sleep disturbances in the same individual, this situation may be very common. For example, since population studies have associated shift work with higher BMI, it is possible that a substantial proportion of shift workers in the United States have OSA, while suffering at the same time from insufficient sleep and circadian misalignment. Another example is that of insomnia with short sleep duration. Lastly, individuals with poor sleep quality, particularly shallow sleep that may be easily fragmented, often have shorter sleep duration. Despite the fact that coexistence of multiple sleep disturbances may be a common condition, there have been few studies addressing the potential metabolic consequences.

In a cross-sectional study of insomnia evaluating glucose regulation by an OGTT, 14 nondiabetic participants with insomnia and short sleep (PSG confirmed sleep efficiency ≤80% and overnight sleeping ≤6 hours) were compared to 14 participants with insomnia and >6 hours of sleep (365). While A1c and glucose values were similar between the two groups, those with insomnia with short-sleep had lower fasting insulin and glucose-stimulated insulin secretion, but increased insulin sensitivity. The authors speculated that these alterations in glucose metabolism could represent an adaptive mechanism in response to increased fuel needs related to the physiologic hyperarousal thought to be a hallmark of insomnia. Furthermore, analyses of the Penn State Cohort, a large prospective study of 1,741 participants who had one night of laboratory PSG and were followed for 14 years, found that men with a complaint of insomnia for ≥1 year who also had a sleep duration of <6 hours on PSG had significantly higher mortality compared to men with “normal sleep duration and no insomnia” (OR 4.00, 95% CI 1.14–13.99) after adjusting for confounders (366). This analysis suggested that “insomnia with short sleep” may be a more biologically severe phenotype than insomnia with normal sleep duration, at least in men. Insomnia with short sleep in women was not associated with increased mortality. In the same cohort, the risk of type 2 diabetes was nearly threefold higher in individuals with insomnia with PSG-defined sleep duration <5 hours, irrespective of sex, while those with insomnia with longer sleep duration did not have an increased risk (48). The fact that sleep duration was assessed via a single night of PSG is a limitation of these Penn State Cohort studies. In another cross-sectional study of 15,227 U.S. Hispanics/Latinos, those with short sleep (self-reported <6 hours) and insomnia were more likely to have diabetes (OR 1.46, 95% CI 1.02–2.11) than average sleepers (>6–9 hours) with insomnia (OR 1.28, 95% CI 1.02–1.61) (367). These associations, however, were attenuated after adjusting for BMI.

A combination between OSA and short sleep duration has been explored in a few studies. In participants of the Korean Genome and Epidemiology Study, the combination of self-reported short sleep duration (<5 hours) and presence of OSA (as assessed by a portable home sleep device) was associated with a much higher risk of having visceral obesity (OR 4.40, 95% CI 1.80–10.77) than sleeping ≥7 hours and not having OSA (368). Interestingly, the adjusted odds ratio for visceral obesity was 2.05 (95% CI 1.09–3.86) in individuals sleeping <5 hours compared with those sleeping >7 hours, while the adjusted odds ratio for visceral obesity was 1.57 (95% CI 1.08–2.26) in individuals with OSA compared with those without OSA. This study thus suggests a synergy in the adverse effects of insufficient sleep and OSA, respectively, on adiposity. Another study in 136 Japanese participants with and without the metabolic syndrome, matched by age and BMI, revealed that the severity of OSA (as measured by a portable monitor) was comparable between the two groups (369). However, participants with the metabolic syndrome had significantly shorter sleep duration (5.8 vs. 6.1 hours) assessed by actigraphy. The combination of insufficient sleep and OSA could potentially also affect glycemic control in type 2 diabetes. In a small study of 71 type 2 diabetes patients with untreated OSA, sleep duration (measured by actigraphy) was inversely associated with A1c, while AHI itself was not. Each hour of reduction in sleep duration was associated with a 4.8% increase in A1c above its reference value (95% CI 1.5–8.0) (370).

Shift workers may be at risk of having sleep disturbances aside from having circadian misalignment. In a study of 26,463 workers in China, shift work was significantly associated with poor sleep quality as assessed by questionnaires. Sleep quality improved after leaving shift work. In another study of 121 hospital employees performing shift work and 150 day-workers, shift work status was associated with poor sleep quality, as well as with the metabolic syndrome (OR 2.29, 95% CI 1.12–4.70) (371). Interestingly, poor sleep quality did not mediate the relationship between shift work and the metabolic syndrome. The combined presence of shift work and OSA has also been explored in a few studies, although none addressed metabolic aspects. Two studies of shift workers with OSA (total 52 participants) found that the AHI assessed by PSG was significantly higher if the PSG was performed after a night shift compared to after a day shift (372,373).

Whether the repeated exposure to a higher severity of OSA during daytime sleep after a night of work may affect the metabolic health of shift workers is not known. Lastly, an experimental study has compared the metabolic impact of 8 days of sleep restriction (5 hours per night) with or without circadian misalignment. The reduction in insulin sensitivity (derived from intravenous glucose tolerance testing) was nearly twofold higher when the subjects were exposed to both insufficient sleep and circadian misalignment than when they were exposed to sleep restriction alone (13).

The existing evidence thus suggests that some combinations of sleep disturbances may be more detrimental to metabolic health than each component alone, but more research in this area is needed.

## Conclusions

Disturbances of different aspects of sleep, including sleep duration, quality, respiratory function during sleep, and circadian timing have all been linked to abnormal glucose metabolism. Epidemiologic studies controlled for age and adiposity in the analyses. Many studies also included some measure of self-perceived stress or of socioeconomic status (e.g., using income and/or education as surrogate measures) in their analyses. The epidemiologic evidence linking sleep and adverse metabolic outcomes has come from a very large number of studies conducted in a wide variety of social and geographic environments, as well as in populations with very different demographic characteristics. Nonetheless, the findings have been remarkably consistent. Well-controlled in-laboratory experiments have provided causative evidence and suggested mechanistic pathways. As the prevalence and costs of care for the metabolic syndrome, type 2 diabetes, and gestational diabetes show no signs of decline, the efficacy and effectiveness of interventions that optimize sleep and circadian function to prevent the development or reduce the severity of these metabolic disorders need to be urgently evaluated.

## List of Abbreviations

A1c: glycosylated hemoglobin
AHI: apnea-hypopnea index
BMI: body mass index
CI: confidence interval
CPAP: continuous positive airway pressure
EEG: electroencephalogram
GHTN: gestational hypertension
HDL: high-density lipoprotein
HOMA/HOMA-IR: homeostatic model assessment, an index of insulin resistance
HPA: hypothalamic-pituitary-adrenal
IGT: impaired glucose tolerance
IL: interleukin
IVGTT: intravenous glucose tolerance test
MSF: mid-time sleep on free days
MT1/MT2: melatonin receptors 1 and 2
NHANES: National Health and Nutrition Examination Survey
NREM: non-REM sleep
OGTT: oral glucose tolerance test
OR: odds ratio
OSA: obstructive sleep apnea
PSG: polysomnography/polysomnogram
PSQI: Pittsburgh Sleep Quality Index
RCT: randomized controlled trial
REM: rapid-eye-movement sleep
ROS: reactive oxygen species
RR: relative risk
SCN: suprachiasmatic nuclei
SWS: slow wave sleep
TNF: tumor necrosis factor

## References

1 National Heart, Lung, and Blood Institute: What are sleep deprivation and deficiency? [article online], 2012. Available from https://www.nhlbi.nih.gov/health/health-topics/topics/sdd. Accessed 31 March 2016
2 Reutrakul S, Van Cauter E: Interactions between sleep, circadian function, and glucose metabolism: implications for risk and severity of diabetes. Ann N Y Acad Sci 1311:151–173, 2014 24628249
3 Koren D, O’Sullivan KL, Mokhlesi B: Metabolic and glycemic sequelae of sleep disturbances in children and adults. Curr Diab Rep 15:562, 2015 25398202
4 Izci-Balserak B, Pien GW: The relationship and potential mechanistic pathways between sleep disturbances and maternal hyperglycemia. Curr Diab Rep 14:459, 2014 24398662
5 National Heart, Lung, and Blood Institute: How much sleep is enough? [article online], 2012. Available from https://www.nhlbi.nih.gov/health/health-topics/topics/sdd/howmuch. Accessed 31 March 2016
6 National Sleep Foundation: 2009 Sleep in America poll—health and safety [article online], 2016. Available from https://sleepfoundation.org/sleep-polls-data/sleep-in-america-poll/2009-health-and-safety. Accessed 31 March 2016
7 Krueger PM, Friedman EM: Sleep duration in the United States: a cross-sectional population-based study. Am J Epidemiol 169:1052–1063, 2009 19299406
8 Spiegel K, Leproult R, Van Cauter E: Impact of sleep debt on metabolic and endocrine function. Lancet 354:1435–1439, 1999 10543671
9 Leproult R, Van Cauter E: Role of sleep and sleep loss in hormonal release and metabolism. Endocr Dev 17:11–21, 2010 19955752
10 Broussard JL, Ehrmann DA, Van Cauter E, Tasali E, Brady MJ: Impaired insulin signaling in human adipocytes after experimental sleep restriction: a randomized, crossover study. Ann Intern Med 157:549–557, 2012 23070488
11 Nedeltcheva AV, Kessler L, Imperial J, Penev PD: Exposure to recurrent sleep restriction in the setting of high caloric intake and physical inactivity results in increased insulin resistance and reduced glucose tolerance. J Clin Endocrinol Metab 94:3242–3250, 2009 19567526
12 Buxton OM, Pavlova M, Reid EW, Wang W, Simonson DC, Adler GK: Sleep restriction for 1 week reduces insulin sensitivity in healthy men. Diabetes 59:2126–2133, 2010 20585000
13 Leproult R, Holmback U, Van Cauter E: Circadian misalignment augments markers of insulin resistance and inflammation, independently of sleep loss. Diabetes 63:1860–1869, 2014 24458353
14 van Leeuwen WM, Hublin C, Sallinen M, Harma M, Hirvonen A, Porkka-Heiskanen T: Prolonged sleep restriction affects glucose metabolism in healthy young men. Int J Endocrinol 2010:108641, 2010 20414467
15 Leproult R, Deliens G, Gilson M, Peigneux P: Beneficial impact of sleep extension on fasting insulin sensitivity in adults with habitual sleep restriction. Sleep 38:707–715, 2015 25348128
16 Killick R, Hoyos CM, Melehan KL, Dungan GC, 2nd, Poh J, Liu PY: Metabolic and hormonal effects of ‘catch-up’ sleep in men with chronic, repetitive, lifestyle-driven sleep restriction. Clin Endocrinol (Oxf) 83:498–507, 2015 25683266
17 Ayas NT, White DP, Al-Delaimy WK, Manson JE, Stampfer MJ, Speizer FE, Patel S, Hu FB: A prospective study of self-reported sleep duration and incident diabetes in women. Diabetes Care 26:380–384, 2003 12547866
18 Beihl DA, Liese AD, Haffner SM: Sleep duration as a risk factor for incident type 2 diabetes in a multiethnic cohort. Ann Epidemiol 19:351–357, 2009 19362278
19 Bjorkelund C, Bondyr-Carlsson D, Lapidus L, Lissner L, Mansson J, Skoog I, Bengtsson C: Sleep disturbances in midlife unrelated to 32-year diabetes incidence: the prospective population study of women in Gothenburg. Diabetes Care 28:2739–2744, 2005 16249549
20 Gangwisch JE, Heymsfield SB, Boden-Albala B, Buijs RM, Kreier F, Pickering TG, Rundle AG, Zammit GK, Malaspina D: Sleep duration as a risk factor for diabetes incidence in a large U.S. sample. Sleep 30:1667–1673, 2007 18246976
21 Holliday EG, Magee CA, Kritharides L, Banks E, Attia J: Short sleep duration is associated with risk of future diabetes but not cardiovascular disease: a prospective study and meta-analysis. PLOS ONE 8:e82305, 2013 24282622
22 Tuomilehto H, Peltonen M, Partinen M, Lavigne G, Eriksson JG, Herder C, Aunola S, Keinanen-Kiukaanniemi S, Ilanne-Parikka P, Uusitupa M, Tuomilehto J, Lindstrom J; Finnish Diabetes Prevention Study Group: Sleep duration, lifestyle intervention, and incidence of type 2 diabetes in impaired glucose tolerance: the Finnish Diabetes Prevention Study. Diabetes Care 32:1965–1971, 2009 19651919
23 von Ruesten A, Weikert C, Fietze I, Boeing H: Association of sleep duration with chronic diseases in the European Prospective Investigation into Cancer and Nutrition (EPIC)-Potsdam study. PLOS ONE 7:e30972, 2012 22295122
24 Xu Q, Song Y, Hollenbeck A, Blair A, Schatzkin A, Chen H: Day napping and short night sleeping are associated with higher risk of diabetes in older adults. Diabetes Care 33:78–83, 2010 19825823
25 Yaggi HK, Araujo AB, McKinlay JB: Sleep duration as a risk factor for the development of type 2 diabetes. Diabetes Care 29:657–661, 2006 16505522
26 Hayashino Y, Fukuhara S, Suzukamo Y, Okamura T, Tanaka T, Ueshima H; HIPOP-OHP Research Group: Relation between sleep quality and quantity, quality of life, and risk of developing diabetes in healthy workers in Japan: the High-risk and Population Strategy for Occupational Health Promotion (HIPOP-OHP) Study. BMC Public Health 7:129, 2007 17597542
27 Mallon L, Broman JE, Hetta J: High incidence of diabetes in men with sleep complaints or short sleep duration: a 12-year follow-up study of a middle-aged population. Diabetes Care 28:2762–2767, 2005 16249553
28 Boyko EJ, Seelig AD, Jacobson IG, Hooper TI, Smith B, Smith TC, Crum-Cianflone NF; Millennium Cohort Study Team: Sleep characteristics, mental health, and diabetes risk: a prospective study of U.S. military service members in the Millennium Cohort Study. Diabetes Care 36:3154–3161, 2013 23835691
29 Kita T, Yoshioka E, Satoh H, Saijo Y, Kawaharada M, Okada E, Kishi R: Short sleep duration and poor sleep quality increase the risk of diabetes in Japanese workers with no family history of diabetes. Diabetes Care 35:313–318, 2012 22210572
30 Chaput JP, Despres JP, Bouchard C, Astrup A, Tremblay A: Sleep duration as a risk factor for the development of type 2 diabetes or impaired glucose tolerance: analyses of the Quebec Family Study. Sleep Med 10:919–924, 2009 19332380
31 Gutierrez-Repiso C, Soriguer F, Rubio-Martin E, Esteva de Antonio I, Ruiz de Adana MS, Almaraz MC, Olveira-Fuster G, Morcillo S, Valdes S, Lago-Sampedro AM, Garcia-Fuentes E, Rojo-Martinez G: Night-time sleep duration and the incidence of obesity and type 2 diabetes. Findings from the prospective Pizarra study. Sleep Med 15:1398–1404, 2014 25262361
32 Heianza Y, Kato K, Fujihara K, Tanaka S, Kodama S, Hanyu O, Sato K, Sone H: Role of sleep duration as a risk factor for type 2 diabetes among adults of different ages in Japan: the Niigata Wellness Study. Diabet Med 31:1363–1367, 2014 25124930
33 Cappuccio FP, D’Elia L, Strazzullo P, Miller MA: Quantity and quality of sleep and incidence of type 2 diabetes: a systematic review and meta-analysis. Diabetes Care 33:414–420, 2010 19910503
34 Knutson KL, Ryden AM, Mander BA, Van Cauter E: Role of sleep duration and quality in the risk and severity of type 2 diabetes mellitus. Arch Intern Med 166:1768–1774, 2006 16983057
35 Ohkuma T, Fujii H, Iwase M, Kikuchi Y, Ogata S, Idewaki Y, Ide H, Doi Y, Hirakawa Y, Nakamura U, Kitazono T: Impact of sleep duration on obesity and the glycemic level in patients with type 2 diabetes: the Fukuoka Diabetes Registry. Diabetes Care 36:611–617, 2013 23150286
36 Kim BK, Kim BS, An SY, Lee MS, Choi YJ, Han SJ, Chung YS, Lee KW, Kim DJ: Sleep duration and glycemic control in patients with diabetes mellitus: Korea National Health and Nutrition Examination Survey 2007–2010. J Korean Med Sci 28:1334–1339, 2013 24015039
37 Zheng Y, Wang A, Pan C, Lu J, Dou J, Lu Z, Ba J, Wang B, Mu Y: Impact of night sleep duration on glycemic and triglyceride levels in Chinese with different glycemic status. J Diabetes 7:24–30, 2015 24981368
38 Knutson KL, Van Cauter E, Zee P, Liu K, Lauderdale DS: Cross-sectional associations between measures of sleep and markers of glucose metabolism among subjects with and without diabetes: the Coronary Artery Risk Development in Young Adults (CARDIA) Sleep Study. Diabetes Care 34:1171–1176, 2011 21411507
39 Trento M, Broglio F, Riganti F, Basile M, Borgo E, Kucich C, Passera P, Tibaldi P, Tomelini M, Cavallo F, Ghigo E, Porta M: Sleep abnormalities in type 2 diabetes may be associated with glycemic control. Acta Diabetol 45:225–229, 2008 18685806
40 Bergman RN: Lilly lecture 1989. Toward physiological understanding of glucose tolerance. Minimal-model approach. Diabetes 38:1512–1527, 1989 2684710
41 Tasali E, Leproult R, Ehrmann DA, Van Cauter E: Slow-wave sleep and the risk of type 2 diabetes in humans. Proc Natl Acad Sci U S A 105:1044–1049, 2008 18172212
42 Stamatakis KA, Punjabi NM: Effects of sleep fragmentation on glucose metabolism in normal subjects. Chest 137:95–101, 2010 19542260
43 American Psychiatric Association: Diagnostic and Statistical Manual of Mental Disorders. 5th ed. Arlington, VA, American Psychiatric Publishing, 2013
44 Engeda J, Mezuk B, Ratliff S, Ning Y: Association between duration and quality of sleep and the risk of pre-diabetes: evidence from NHANES. Diabet Med 30:676–680, 2013 23425048
45 Liu J, Hay J, Faught BE: The association of sleep disorder, obesity status, and diabetes mellitus among US adults—the NHANES 2009–2010 survey results. Int J Endocrinol 2013:234129, 2013 23956743
46 Foley D, Ancoli-Israel S, Britz P, Walsh J: Sleep disturbances and chronic disease in older adults: results of the 2003 National Sleep Foundation Sleep in America Survey. J Psychosom Res 56:497–502, 2004 15172205
47 Budhiraja R, Roth T, Hudgel DW, Budhiraja P, Drake CL: Prevalence and polysomnographic correlates of insomnia comorbid with medical disorders. Sleep 34:859–867, 2011 21731135
48 Vgontzas AN, Liao D, Pejovic S, Calhoun S, Karataraki M, Bixler EO: Insomnia with objective short sleep duration is associated with type 2 diabetes: a population-based study. Diabetes Care 32:1980–1985, 2009 19641160
49 Eriksson AK, Ekbom A, Granath F, Hilding A, Efendic S, Ostenson CG: Psychological distress and risk of pre-diabetes and type 2 diabetes in a prospective study of Swedish middle-aged men and women. Diabet Med 25:834–842, 2008 18513304
50 Kawakami N, Takatsuka N, Shimizu H: Sleep disturbance and onset of type 2 diabetes. Diabetes Care 27:282–283, 2004 14694011
51 Meisinger C, Heier M, Loewel H; MONICA/KORA Augsburg Cohort Study: Sleep disturbance as a predictor of type 2 diabetes mellitus in men and women from the general population. Diabetologia 48:235–241, 2005 15645205
52 Nilsson PM, Roost M, Engstrom G, Hedblad B, Berglund G: Incidence of diabetes in middle-aged men is related to sleep disturbances. Diabetes Care 27:2464–2469, 2004 15451917
53 Olsson L, Ahlbom A, Grill V, Midthjell K, Carlsson S: Sleep disturbances and low psychological well-being are associated with an increased risk of autoimmune diabetes in adults. Results from the Nord-Trondelag Health Study. Diabetes Res Clin Pract 98:302–311, 2012 23010555
54 Rod NH, Vahtera J, Westerlund H, Kivimaki M, Zins M, Goldberg M, Lange T: Sleep disturbances and cause-specific mortality: results from the GAZEL cohort study. Am J Epidemiol 173:300–309, 2011 21193534
55 Zhang J, Lam SP, Li SX, Li AM, Wing YK: The longitudinal course and impact of non-restorative sleep: a five-year community-based follow-up study. Sleep Med 13:570–576, 2012 22445230
56 Knowler WC, Pettitt DJ, Savage PJ, Bennett PH: Diabetes incidence in Pima Indians: contributions of obesity and parental diabetes. Am J Epidemiol 113:144–156, 1981 7468572
57 Shaten BJ, Smith GD, Kuller LH, Neaton JD: Risk factors for the development of type II diabetes among men enrolled in the usual care group of the Multiple Risk Factor Intervention Trial. Diabetes Care 16:1331–1339, 1993 8269790
58 Burchfiel CM, Curb JD, Rodriguez BL, Yano K, Hwang LJ, Fong KO, Marcus EB: Incidence and predictors of diabetes in Japanese-American men. The Honolulu Heart Program. Ann Epidemiol 5:33–43, 1995 7728283
59 Sargeant LA, Wareham NJ, Khaw KT: Family history of diabetes identifies a group at increased risk for the metabolic consequences of obesity and physical inactivity in EPIC-Norfolk: a population-based study. The European Prospective Investigation into Cancer. Int J Obes Relat Metab Disord 24:1333–1339, 2000 11093296
60 Harrison TA, Hindorff LA, Kim H, Wines RC, Bowen DJ, McGrath BB, Edwards KL: Family history of diabetes as a potential public health tool. Am J Prev Med 24:152–159, 2003 12568821
61 Erasmus RT, Blanco Blanco E, Okesina AB, Mesa Arana J, Gqweta Z, Matsha T: Importance of family history in type 2 black South African diabetic patients. Postgrad Med J 77:323–325, 2001 11320276
62 Tsai YW, Kann NH, Tung TH, Chao YJ, Lin CJ, Chang KC, Chang SS, Chen JY: Impact of subjective sleep quality on glycemic control in type 2 diabetes mellitus. Fam Pract 29:30–35, 2012 21795758
63 Tang Y, Meng L, Li D, Yang M, Zhu Y, Li C, Jiang Z, Yu P, Li Z, Song H, Ni C: Interaction of sleep quality and sleep duration on glycemic control in patients with type 2 diabetes mellitus. Chin Med J (Engl) 127:3543–3547, 2014 25316226
64 Kushida CA, Chang A, Gadkary C, Guilleminault C, Carrillo O, Dement WC: Comparison of actigraphic, polysomnographic, and subjective assessment of sleep parameters in sleep-disordered patients. Sleep Med 2:389–396, 2001 14592388
65 Chasens ER, Yang K: Insomnia and physical activity in adults with prediabetes. Clin Nurs Res 21:294–308, 2012 21788447
66 Thomas M, Sing H, Belenky G, Holcomb H, Mayberg H, Dannals R, Wagner H, Thorne D, Popp K, Rowland L, Welsh A, Balwinski S, Redmond D: Neural basis of alertness and cognitive performance impairments during sleepiness. I. Effects of 24 h of sleep deprivation on waking human regional brain activity. J Sleep Res 9:335–352, 2000 11123521
67 Grassi G, Dell’Oro R, Quarti-Trevano F, Scopelliti F, Seravalle G, Paleari F, Gamba PL, Mancia G: Neuroadrenergic and reflex abnormalities in patients with metabolic syndrome. Diabetologia 48:1359–1365, 2005 15933859
68 Tentolouris N, Argyrakopoulou G, Katsilambros N: Perturbed autonomic nervous system function in metabolic syndrome. Neuromolecular Med 10:169–178, 2008 18224460
69 Irwin M, Thompson J, Miller C, Gillin JC, Ziegler M: Effects of sleep and sleep deprivation on catecholamine and interleukin-2 levels in humans: clinical implications. J Clin Endocrinol Metab 84:1979–1985, 1999 10372697
70 Reynolds AC, Dorrian J, Liu PY, Van Dongen HP, Wittert GA, Harmer LJ, Banks S: Impact of five nights of sleep restriction on glucose metabolism, leptin and testosterone in young adult men. PLOS ONE 7:e41218, 2012 22844441
71 Leproult R, Copinschi G, Buxton O, Van Cauter E: Sleep loss results in an elevation of cortisol levels the next evening. Sleep 20:865–870, 1997 9415946
72 Plat L, Leproult R, L’Hermite-Baleriaux M, Fery F, Mockel J, Polonsky KS, Van Cauter E: Metabolic effects of short-term elevations of plasma cortisol are more pronounced in the evening than in the morning. J Clin Endocrinol Metab 84:3082–3092, 1999 10487669
73 Stamatakis KA, Punjabi NM: Effects of sleep fragmentation on glucose metabolism in normal subjects. Chest 137:95–101, 2010 19542260
74 Mullington JM, Simpson NS, Meier-Ewert HK, Haack M: Sleep loss and inflammation. Best Pract Res Clin Endocrinol Metab 24:775–784, 2010 21112025
75 Boudjeltia KZ, Faraut B, Stenuit P, Esposito MJ, Dyzma M, Brohee D, Ducobu J, Vanhaeverbeek M, Kerkhofs M: Sleep restriction increases white blood cells, mainly neutrophil count, in young healthy men: a pilot study. Vasc Health Risk Manag 4:1467–1470, 2008 19337560
76 Faraut B, Boudjeltia KZ, Dyzma M, Rousseau A, David E, Stenuit P, Franck T, Van Antwerpen P, Vanhaeverbeek M, Kerkhofs M: Benefits of napping and an extended duration of recovery sleep on alertness and immune cells after acute sleep restriction. Brain Behav Immun 25:16–24, 2011 20699115
77 Boyum A, Wiik P, Gustavsson E, Veiby OP, Reseland J, Haugen AH, Opstad PK: The effect of strenuous exercise, calorie deficiency and sleep deprivation on white blood cells, plasma immunoglobulins and cytokines. Scand J Immunol 43:228–235, 1996 8633203
78 Vgontzas AN, Zoumakis E, Bixler EO, Lin HM, Follett H, Kales A, Chrousos GP: Adverse effects of modest sleep restriction on sleepiness, performance, and inflammatory cytokines. J Clin Endocrinol Metab 89:2119–2126, 2004 15126529
79 Irwin MR, Wang M, Campomayor CO, Collado-Hidalgo A, Cole S: Sleep deprivation and activation of morning levels of cellular and genomic markers of inflammation. Arch Intern Med 166:1756–1762, 2006 16983055
80 van Leeuwen WM, Lehto M, Karisola P, Lindholm H, Luukkonen R, Sallinen M, Harma M, Porkka-Heiskanen T, Alenius H: Sleep restriction increases the risk of developing cardiovascular diseases by augmenting proinflammatory responses through IL-17 and CRP. PLOS ONE 4:e4589, 2009 19240794
81 Shearer WT, Reuben JM, Mullington JM, Price NJ, Lee BN, Smith EO, Szuba MP, Van Dongen HP, Dinges DF: Soluble TNF-alpha receptor 1 and IL-6 plasma levels in humans subjected to the sleep deprivation model of spaceflight. J Allergy Clin Immunol 107:165–170, 2001 11150007
82 Wieser V, Moschen AR, Tilg H: Inflammation, cytokines and insulin resistance: a clinical perspective. Arch Immunol Ther Exp (Warsz) 61:119–125, 2013 23307037
83 Spiegel K, Tasali E, Penev P, Van Cauter E: Brief communication: sleep curtailment in healthy young men is associated with decreased leptin levels, elevated ghrelin levels, and increased hunger and appetite. Ann Intern Med 141:846–850, 2004 15583226
84 Morselli LL, Guyon A, Spiegel K: Sleep and metabolic function. Pflugers Arch 463:139–160, 2012 22101912
85 Killick R, Banks S, Liu PY: Implications of sleep restriction and recovery on metabolic outcomes. J Clin Endocrinol Metab 97:3876–3890, 2012 22996147
86 Guilleminault C, Powell NB, Martinez S, Kushida C, Raffray T, Palombini L, Philip P: Preliminary observations on the effects of sleep time in a sleep restriction paradigm. Sleep Med 4:177–184, 2003 14592319
87 Spiegel K, Leproult R, L’Hermite-Baleriaux M, Copinschi G, Penev PD, Van Cauter E: Leptin levels are dependent on sleep duration: relationships with sympathovagal balance, carbohydrate regulation, cortisol, and thyrotropin. J Clin Endocrinol Metab 89:5762–5771, 2004 15531540
88 Mullington JM, Chan JL, Van Dongen HP, Szuba MP, Samaras J, Price NJ, Meier-Ewert HK, Dinges DF, Mantzoros CS: Sleep loss reduces diurnal rhythm amplitude of leptin in healthy men. J Neuroendocrinol 15:851–854, 2003 12899679
89 Hanlon EC, Tasali E, Leproult R, Stuhr KL, Doncheck E, de Wit H, Hillard CJ, Van Cauter E: Sleep restriction enhances the daily rhythm of circulating levels of endocannabinoid 2-arachidonoylglycerol. Sleep 39:653–664, 2016 26612385
90 Broussard JL, Kilkus JM, Delebecque F, Abraham V, Day A, Whitmore HR, Tasali E: Elevated ghrelin predicts food intake during experimental sleep restriction. Obesity (Silver Spring) 24:132–138, 2016 26467988
91 Nedeltcheva AV, Kilkus JM, Imperial J, Schoeller DA, Penev PD: Insufficient sleep undermines dietary efforts to reduce adiposity. Ann Intern Med 153:435–441, 2010 20921542
92 Omisade A, Buxton OM, Rusak B: Impact of acute sleep restriction on cortisol and leptin levels in young women. Physiol Behav 99:651–656, 2010 20138072
93 Schmid SM, Hallschmid M, Jauch-Chara K, Born J, Schultes B: A single night of sleep deprivation increases ghrelin levels and feelings of hunger in normal-weight healthy men. J Sleep Res 17:331–334, 2008 18564298
94 Knutson KL, Galli G, Zhao X, Mattingly M, Cizza G; NIDDK Sleep Extension Study: No association between leptin levels and sleep duration or quality in obese adults. Obesity (Silver Spring) 19:2433–2435, 2011 21799479
95 Taheri S, Lin L, Austin D, Young T, Mignot E: Short sleep duration is associated with reduced leptin, elevated ghrelin, and increased body mass index. PLOS Med 1:e62, 2004 15602591
96 Nedeltcheva AV, Kilkus JM, Imperial J, Kasza K, Schoeller DA, Penev PD: Sleep curtailment is accompanied by increased intake of calories from snacks. Am J Clin Nutr 89:126–133, 2009 19056602
97 Bosy-Westphal A, Hinrichs S, Jauch-Chara K, Hitze B, Later W, Wilms B, Settler U, Peters A, Kiosz D, Muller MJ: Influence of partial sleep deprivation on energy balance and insulin sensitivity in healthy women. Obes Facts 1:266–273, 2008 20054188
98 St-Onge MP, Roberts AL, Chen J, Kelleman M, O’Keeffe M, RoyChoudhury A, Jones PJ: Short sleep duration increases energy intakes but does not change energy expenditure in normal-weight individuals. Am J Clin Nutr 94:410–416, 2011 21715510
99 Markwald RR, Melanson EL, Smith MR, Higgins J, Perreault L, Eckel RH, Wright KP, Jr.: Impact of insufficient sleep on total daily energy expenditure, food intake, and weight gain. Proc Natl Acad Sci U S A 110:5695–5700, 2013 23479616
100 Spaeth AM, Dinges DF, Goel N: Effects of experimental sleep restriction on weight gain, caloric intake, and meal timing in healthy adults. Sleep 36:981–990, 2013 23814334
101 Schmid SM, Hallschmid M, Jauch-Chara K, Wilms B, Benedict C, Lehnert H, Born J, Schultes B: Short-term sleep loss decreases physical activity under free-living conditions but does not increase food intake under time-deprived laboratory conditions in healthy men. Am J Clin Nutr 90:1476–1482, 2009 19846546
102 Benedict C, Brooks SJ, O’Daly OG, Almen MS, Morell A, Aberg K, Gingnell M, Schultes B, Hallschmid M, Broman JE, Larsson EM, Schioth HB: Acute sleep deprivation enhances the brain’s response to hedonic food stimuli: an fMRI study. J Clin Endocrinol Metab 97:E443–E447, 2012 22259064
103 St-Onge MP, McReynolds A, Trivedi ZB, Roberts AL, Sy M, Hirsch J: Sleep restriction leads to increased activation of brain regions sensitive to food stimuli. Am J Clin Nutr 95:818–824, 2012 22357722
104 Jung CM, Melanson EL, Frydendall EJ, Perreault L, Eckel RH, Wright KP: Energy expenditure during sleep, sleep deprivation and sleep following sleep deprivation in adult humans. J Physiol 589:235–244, 2011 21059762
105 Bromley LE, Booth JN, 3rd, Kilkus JM, Imperial JG, Penev PD: Sleep restriction decreases the physical activity of adults at risk for type 2 diabetes. Sleep 35:977–984, 2012 22754044
106 Booth JN, Bromley LE, Darukhanavala AP, Whitmore HR, Imperial JG, Penev PD: Reduced physical activity in adults at risk for type 2 diabetes who curtail their sleep. Obesity (Silver Spring) 20:278–284, 2012 21996665
107 Lopez-Garcia E, Faubel R, Leon-Munoz L, Zuluaga MC, Banegas JR, Rodriguez-Artalejo F: Sleep duration, general and abdominal obesity, and weight change among the older adult population of Spain. Am J Clin Nutr 87:310–316, 2008 18258619
108 Hairston KG, Bryer-Ash M, Norris JM, Haffner S, Bowden DW, Wagenknecht LE: Sleep duration and five-year abdominal fat accumulation in a minority cohort: the IRAS family study. Sleep 33:289–295, 2010 20337186
109 Watanabe M, Kikuchi H, Tanaka K, Takahashi M: Association of short sleep duration with weight gain and obesity at 1-year follow-up: a large-scale prospective study. Sleep 33:161–167, 2010 20175399
110 Chaput JP, Despres JP, Bouchard C, Tremblay A: The association between sleep duration and weight gain in adults: a 6-year prospective study from the Quebec Family Study. Sleep 31:517–523, 2008 18457239
111 Broussard J, Brady MJ: The impact of sleep disturbances on adipocyte function and lipid metabolism. Best Pract Res Clin Endocrinol Metab 24:763–773, 2010 21112024
112 Ahima RS, Saper CB, Flier JS, Elmquist JK: Leptin regulation of neuroendocrine systems. Front Neuroendocrinol 21:263–307, 2000 10882542
113 Hucking K, Hamilton-Wessler M, Ellmerer M, Bergman RN: Burst-like control of lipolysis by the sympathetic nervous system in vivo. J Clin Invest 111:257–264, 2003 12531882
114 Broussard JL, Chapotot F, Abraham V, Day A, Delebecque F, Whitmore HR, Tasali E: Sleep restriction increases free fatty acids in healthy men. Diabetologia 58:791–798, 2015 25702040
115 Knutson KL, Leproult R: Apples to oranges: comparing long sleep to short sleep. J Sleep Res 19:118, 2010 20470264
116 Punjabi NM: The epidemiology of adult obstructive sleep apnea. Proc Am Thorac Soc 5:136–143, 2008 18250205
117 Peppard PE, Young T, Barnet JH, Palta M, Hagen EW, Hla KM: Increased prevalence of sleep-disordered breathing in adults. Am J Epidemiol 177:1006–1014, 2013 23589584
118 Young T, Evans L, Finn L, Palta M: Estimation of the clinically diagnosed proportion of sleep apnea syndrome in middle-aged men and women. Sleep 20:705–706, 1997 9406321
119 Kapur V, Strohl KP, Redline S, Iber C, O’Connor G, Nieto J: Underdiagnosis of sleep apnea syndrome in U.S. communities. Sleep Breath 6:49–54, 2002 12075479
120 Sleep-related breathing disorders in adults: recommendations for syndrome definition and measurement techniques in clinical research. The Report of an American Academy of Sleep Medicine Task Force. Sleep 22:667–689, 1999 10450601
121 Aurora RN, Punjabi NM: Obstructive sleep apnoea and type 2 diabetes mellitus: a bidirectional association. Lancet Respir Med 1:329–338, 2013 24429158
122 Louis M, Punjabi NM: Effects of acute intermittent hypoxia on glucose metabolism in awake healthy volunteers. J Appl Physiol 106:1538–1544, 2009 19265062
123 Punjabi NM, Shahar E, Redline S, Gottlieb DJ, Givelber R, Resnick HE; Sleep Heart Health Study Investigators: Sleep-disordered breathing, glucose intolerance, and insulin resistance: the Sleep Heart Health Study. Am J Epidemiol 160:521–530, 2004 15353412
124 Reichmuth KJ, Austin D, Skatrud JB, Young T: Association of sleep apnea and type II diabetes: a population-based study. Am J Respir Crit Care Med 172:1590–1595, 2005 16192452
125 Botros N, Concato J, Mohsenin V, Selim B, Doctor K, Yaggi HK: Obstructive sleep apnea as a risk factor for type 2 diabetes. Am J Med 122:1122–1127, 2009 19958890
126 Celen YT, Hedner J, Carlson J, Peker Y: Impact of gender on incident diabetes mellitus in obstructive sleep apnea: a 16-year follow-up. J Clin Sleep Med 6:244–250, 2010 20572417
127 Lindberg E, Theorell-Haglow J, Svensson M, Gislason T, Berne C, Janson C: Sleep apnea and glucose metabolism: a long-term follow-up in a community-based sample. Chest 142:935–942, 2012 22499826
128 Marshall NS, Wong KK, Phillips CL, Liu PY, Knuiman MW, Grunstein RR: Is sleep apnea an independent risk factor for prevalent and incident diabetes in the Busselton Health Study? J Clin Sleep Med 5:15–20, 2009 19317376
129 Muraki I, Tanigawa T, Yamagishi K, Sakurai S, Ohira T, Imano H, Kiyama M, Kitamura A, Sato S, Shimamoto T, Konishi M, Iso H; CIRCS Investigators: Nocturnal intermittent hypoxia and metabolic syndrome; the effect of being overweight: the CIRCS study. J Atheroscler Thromb 17:369–377, 2010 20103974
130 Appleton SL, Vakulin A, McEvoy RD, Wittert GA, Martin SA, Grant JF, Taylor AW, Antic NA, Catcheside PG, Adams RJ: Nocturnal hypoxemia and severe obstructive sleep apnea are associated with incident type 2 diabetes in a population cohort of men. J Clin Sleep Med 11:609–614, 2015 25766697
131 Kendzerska T, Gershon AS, Hawker G, Tomlinson G, Leung RS: Obstructive sleep apnea and incident diabetes. A historical cohort study. Am J Respir Crit Care Med 190:218–225, 2014 24897551
132 Wang X, Bi Y, Zhang Q, Pan F: Obstructive sleep apnoea and the risk of type 2 diabetes: a meta-analysis of prospective cohort studies. Respirology 18:140–146, 2013 22988888
133 Aronsohn RS, Whitmore H, Van Cauter E, Tasali E: Impact of untreated obstructive sleep apnea on glucose control in type 2 diabetes. Am J Respir Crit Care Med 181:507–513, 2010 20019340
134 Foster GD, Sanders MH, Millman R, Zammit G, Borradaile KE, Newman AB, Wadden TA, Kelley D, Wing RR, Sunyer FX, Darcey V, Kuna ST; Sleep AHEAD Research Group: Obstructive sleep apnea among obese patients with type 2 diabetes. Diabetes Care 32:1017–1019, 2009 19279303
135 Resnick HE, Redline S, Shahar E, Gilpin A, Newman A, Walter R, Ewy GA, Howard BV, Punjabi NM; Sleep Heart Health Study: Diabetes and sleep disturbances: findings from the Sleep Heart Health Study. Diabetes Care 26:702–709, 2003 12610025
136 Laaban JP, Daenen S, Leger D, Pascal S, Bayon V, Slama G, Elgrably F: Prevalence and predictive factors of sleep apnoea syndrome in type 2 diabetic patients. Diabetes Metab 35:372–377, 2009 19683953
137 Einhorn D, Stewart DA, Erman MK, Gordon N, Philis-Tsimikas A, Casal E: Prevalence of sleep apnea in a population of adults with type 2 diabetes mellitus. Endocr Pract 13:355–362, 2007 17669711
138 Harada Y, Oga T, Chin K, Takegami M, Takahashi K, Sumi K, Nakamura T, Nakayama-Ashida Y, Minami I, Horita S, Oka Y, Wakamura T, Fukuhara S, Mishima M, Kadotani H: Differences in relationships among sleep apnoea, glucose level, sleep duration and sleepiness between persons with and without type 2 diabetes. J Sleep Res 21:410–418, 2012 22320933
139 Pillai A, Warren G, Gunathilake W, Idris I: Effects of sleep apnea severity on glycemic control in patients with type 2 diabetes prior to continuous positive airway pressure treatment. Diabetes Technol Ther 13:945–949, 2011 21714680
140 Heffner JE, Rozenfeld Y, Kai M, Stephens EA, Brown LK: Prevalence of diagnosed sleep apnea among patients with type 2 diabetes in primary care. Chest 141:1414–1421, 2012 22095313
141 St-Onge MP, Zammit G, Reboussin DM, Kuna ST, Sanders MH, Millman R, Newman AB, Wadden TA, Wing RR, Pi-Sunyer FX, Foster GD; Sleep AHEAD Research Group: Associations of sleep disturbance and duration with metabolic risk factors in obese persons with type 2 diabetes: data from the Sleep AHEAD Study. Nat Sci Sleep 4:143–150, 2012 23620687
142 Kosseifi S, Bailey B, Price R, Roy TM, Byrd RP, Jr., Peiris AN: The association between obstructive sleep apnea syndrome and microvascular complications in well-controlled diabetic patients. Mil Med 175:913–916, 2010 21121505
143 Tahrani AA, Ali A, Raymond NT, Begum S, Dubb K, Mughal S, Jose B, Piya MK, Barnett AH, Stevens MJ: Obstructive sleep apnea and diabetic neuropathy: a novel association in patients with type 2 diabetes. Am J Respir Crit Care Med 186:434–441, 2012 22723291
144 Rudrappa S, Warren G, Idris I: Obstructive sleep apnoea is associated with the development and progression of diabetic retinopathy, independent of conventional risk factors and novel biomarkers for diabetic retinopathy. Br J Ophthalmol 96:1535, 2012 23077225
145 Fenik VB, Davies RO, Kubin L: REM sleep-like atonia of hypoglossal (XII) moto-neurons is caused by loss of noradrenergic and serotonergic inputs. Am J Respir Crit Care Med 172:1322–1330, 2005 16100007
146 Mokhlesi B, Punjabi NM: “REM-related” obstructive sleep apnea: an epiphenomenon or a clinically important entity? Sleep 35:5–7, 2012 22215911
147 Findley LJ, Wilhoit SC, Suratt PM: Apnea duration and hypoxemia during REM sleep in patients with obstructive sleep apnea. Chest 87:432–436, 1985 3979129
148 Grimaldi D, Beccuti G, Touma C, Van Cauter E, Mokhlesi B: Association of obstructive sleep apnea in rapid eye movement sleep with reduced glycemic control in type 2 diabetes: therapeutic implications. Diabetes Care 37:355–363, 2014 24101701
149 Reichmuth KJ, Austin D, Skatrud JB, Young T: Association of sleep apnea and type II diabetes: a population-based study. Am J Respir Crit Care Med 172:1590–1595, 2005 16192452
150 Punjabi NM; Workshop Participants: Do sleep disorders and associated treatments impact glucose metabolism? Drugs 69(Suppl 2):13–27, 2009 20047348
151 Chakhtoura M, Azar ST: Continuous positive airway pressure and type 2 diabetes mellitus. Diabetes Metab Syndr 6:176–179, 2012 23158985
152 Harsch IA, Schahin SP, Radespiel-Troger M, Weintz O, Jahreiss H, Fuchs FS, Wiest GH, Hahn EG, Lohmann T, Konturek PC, Ficker JH: Continuous positive airway pressure treatment rapidly improves insulin sensitivity in patients with obstructive sleep apnea syndrome. Am J Respir Crit Care Med 169:156–162, 2004 14512265
153 Coughlin SR, Mawdsley L, Mugarza JA, Wilding JP, Calverley PM: Cardiovascular and metabolic effects of CPAP in obese males with OSA. Eur Respir J 29:720–727, 2007 17251237
154 West SD, Nicoll DJ, Wallace TM, Matthews DR, Stradling JR: Effect of CPAP on insulin resistance and HbA1c in men with obstructive sleep apnoea and type 2 diabetes. Thorax 62:969–974, 2007 17557769
155 Nguyen PK, Katikireddy CK, McConnell MV, Kushida C, Yang PC: Nasal continuous positive airway pressure improves myocardial perfusion reserve and endothelial-dependent vasodilation in patients with obstructive sleep apnea. J Cardiovasc Magn Reson 12:50, 2010 20815898
156 Kohler M, Stoewhas AC, Ayers L, Senn O, Bloch KE, Russi EW, Stradling JR: Effects of continuous positive airway pressure therapy withdrawal in patients with obstructive sleep apnea: a randomized controlled trial. Am J Respir Crit Care Med 184:1192–1199, 2011 21836134
157 Sivam S, Phillips CL, Trenell MI, Yee BJ, Liu PY, Wong KK, Grunstein RR: Effects of 8 weeks of continuous positive airway pressure on abdominal adiposity in obstructive sleep apnoea. Eur Respir J 40:913–918, 2012 22267762
158 Hoyos CM, Killick R, Yee BJ, Phillips CL, Grunstein RR, Liu PY: Cardiometabolic changes after continuous positive airway pressure for obstructive sleep apnoea: a randomised sham-controlled study. Thorax 67:1081–1089, 2012 22561530
159 Lam JC, Lam B, Yao TJ, Lai AY, Ooi CG, Tam S, Lam KS, Ip MS: A randomised controlled trial of nasal continuous positive airway pressure on insulin sensitivity in obstructive sleep apnoea. Eur Respir J 35:138–145, 2010 19608589
160 Weinstock TG, Wang X, Rueschman M, Ismail-Beigi F, Aylor J, Babineau DC, Mehra R, Redline S: A controlled trial of CPAP therapy on metabolic control in individuals with impaired glucose tolerance and sleep apnea. Sleep 35:617–625B, 2012 22547887
161 Shaw JE, Punjabi NM, Naughton MT, Willes L, Bergenstal RM, Cistulli PA, Fulcher GR, Richards GN, Zimmet PZ: The effect of treatment of obstructive sleep apnea on glycemic control in type 2 diabetes. Am J Respir Crit Care Med 194:486–492, 2016 26926656
162 Iftikhar IH, Blankfield RP: Effect of continuous positive airway pressure on hemoglobin A(1c) in patients with obstructive sleep apnea: a systematic review and meta-analysis. Lung 190:605–611, 2012 22773248
163 Yang D, Liu Z, Yang H, Luo Q: Effects of continuous positive airway pressure on glycemic control and insulin resistance in patients with obstructive sleep apnea: a meta-analysis. Sleep Breath 17:33–38, 2013 22411171
164 Hecht L, Mohler R, Meyer G: Effects of CPAP-respiration on markers of glucose metabolism in patients with obstructive sleep apnoea syndrome: a systematic review and meta-analysis. Ger Med Sci 9:Doc20, 2011 21863134
165 Chen L, Pei JH, Chen HM: Effects of continuous positive airway pressure treatment on glycaemic control and insulin sensitivity in patients with obstructive sleep apnoea and type 2 diabetes: a meta-analysis. Arch Med Sci 10:637–642, 2014 25276145
166 Iftikhar IH, Khan MF, Das A, Magalang UJ: Meta-analysis: continuous positive airway pressure improves insulin resistance in patients with sleep apnea without diabetes. Ann Am Thorac Soc 10:115–120, 2013 23607839
167 Pamidi S, Wroblewski K, Stepien M, Sharif-Sidi K, Kilkus J, Whitmore H, Tasali E: Eight hours of nightly continuous positive airway pressure treatment of obstructive sleep apnea improves glucose metabolism in patients with prediabetes. A randomized controlled trial. Am J Respir Crit Care Med 192:96–105, 2015 25897569
168 Moon K, Punjabi NM, Aurora RN: Obstructive sleep apnea and type 2 diabetes in older adults. Clin Geriatr Med 31:139–147, ix, 2015 25453306
169 Narkiewicz K, Somers VK: Sympathetic nerve activity in obstructive sleep apnoea. Acta Physiol Scand 177:385–390, 2003 12609010
170 Narkiewicz K, van de Borne PJ, Montano N, Dyken ME, Phillips BG, Somers VK: Contribution of tonic chemoreflex activation to sympathetic activity and blood pressure in patients with obstructive sleep apnea. Circulation 97:943–945, 1998 9529260
171 Narkiewicz K, van de Borne PJ, Pesek CA, Dyken ME, Montano N, Somers VK: Selective potentiation of peripheral chemoreflex sensitivity in obstructive sleep apnea. Circulation 99:1183–1189, 1999 10069786
172 Loredo JS, Ziegler MG, Ancoli-Israel S, Clausen JL, Dimsdale JE: Relationship of arousals from sleep to sympathetic nervous system activity and BP in obstructive sleep apnea. Chest 116:655–659, 1999 10492267
173 Horner RL, Brooks D, Kozar LF, Tse S, Phillipson EA: Immediate effects of arousal from sleep on cardiac autonomic outflow in the absence of breathing in dogs. J Appl Physiol 79:151–162, 1995 7559214
174 Nonogaki K: New insights into sympathetic regulation of glucose and fat metabolism. Diabetologia 43:533–549, 2000 10855527
175 Deibert DC, DeFronzo RA: Epinephrine-induced insulin resistance in man. J Clin Invest 65:717–721, 1980 6243677
176 Avogaro A, Toffolo G, Valerio A, Cobelli C: Epinephrine exerts opposite effects on peripheral glucose disposal and glucose-stimulated insulin secretion. A stable label intravenous glucose tolerance test minimal model study. Diabetes 45:1373–1378, 1996 8826974
177 Raz I, Katz A, Spencer MK: Epinephrine inhibits insulin-mediated glycogenesis but enhances glycolysis in human skeletal muscle. Am J Physiol 260:E430–E435, 1991 1900669
178 Lafontan M, Berlan M: Fat cell alpha 2-adrenoceptors: the regulation of fat cell function and lipolysis. Endocr Rev 16:716–738, 1995 8747832
179 Roden M, Price TB, Perseghin G, Petersen KF, Rothman DL, Cline GW, Shulman GI: Mechanism of free fatty acid-induced insulin resistance in humans. J Clin Invest 97:2859–2865, 1996 8675698
180 Santomauro AT, Boden G, Silva ME, Rocha DM, Santos RF, Ursich MJ, Strassmann PG, Wajchenberg BL: Overnight lowering of free fatty acids with Acipimox improves insulin resistance and glucose tolerance in obese diabetic and nondiabetic subjects. Diabetes 48:1836–1841, 1999 10480616
181 Julius S, Gudbrandsson T, Jamerson K, Andersson O: The interconnection between sympathetics, microcirculation, and insulin resistance in hypertension. Blood Press 1:9–19, 1992 1345145
182 Jamerson KA, Julius S, Gudbrandsson T, Andersson O, Brant DO: Reflex sympathetic activation induces acute insulin resistance in the human forearm. Hypertension 21:618–623, 1993 8491496
183 Zeman RJ, Ludemann R, Easton TG, Etlinger JD: Slow to fast alterations in skeletal muscle fibers caused by clenbuterol, a beta 2-receptor agonist. Am J Physiol 254:E726–E732, 1988 3377073
184 Klein J, Fasshauer M, Ito M, Lowell BB, Benito M, Kahn CR: Beta(3)-adrenergic stimulation differentially inhibits insulin signaling and decreases insulin-induced glucose uptake in brown adipocytes. J Biol Chem 274:34795–34802, 1999 10574950
185 Moncloa F, Velasco I, Beteta L: Plasma cortisol concentration and disappearance rate of 4-14C-cortisol in newcomers to high altitude. J Clin Endocrinol Metab 28:379–382, 1968 5642689
186 Humpeler E, Skrabal F, Bartsch G: Influence of exposure to moderate altitude on the plasma concentraton of cortisol, aldosterone, renin, testosterone, and gonadotropins. Eur J Appl Physiol Occup Physiol 45:167–176, 1980 6780338
187 Maresh CM, Noble BJ, Robertson KL, Harvey JS, Jr.: Aldosterone, cortisol, and electrolyte responses to hypobaric hypoxia in moderate-altitude natives. Aviat Space Environ Med 56:1078–1084, 1985 4074261
188 Anand IS, Chandrashekhar Y, Rao SK, Malhotra RM, Ferrari R, Chandana J, Ramesh B, Shetty KJ, Boparai MS: Body fluid compartments, renal blood flow, and hormones at 6,000 m in normal subjects. J Appl Physiol 74:1234–1239, 1993 8482663
189 Obminski Z, Golec L, Stupnicki R, Hackney AC: Effects of hypobaric-hypoxia on the salivary cortisol levels of aircraft pilots. Aviat Space Environ Med 68:183–186, 1997 9056024
190 Barnholt KE, Hoffman AR, Rock PB, Muza SR, Fulco CS, Braun B, Holloway L, Mazzeo RS, Cymerman A, Friedlander AL: Endocrine responses to acute and chronic high-altitude exposure (4,300 meters): modulating effects of caloric restriction. Am J Physiol Endocrinol Metab 290:E1078–E1088, 2006 16380390
191 Coste O, Beers PV, Bogdan A, Charbuy H, Touitou Y: Hypoxic alterations of cortisol circadian rhythm in man after simulation of a long duration flight. Steroids 70:803–810, 2005 16019044
192 Follenius M, Brandenberger G, Bandesapt JJ, Libert JP, Ehrhart J: Nocturnal cortisol release in relation to sleep structure. Sleep 15:21–27, 1992 1557591
193 Spath-Schwalbe E, Gofferje M, Kern W, Born J, Fehm HL: Sleep disruption alters nocturnal ACTH and cortisol secretory patterns. Biol Psychiatry 29:575–584, 1991 1647222
194 Dinneen S, Alzaid A, Miles J, Rizza R: Metabolic effects of the nocturnal rise in cortisol on carbohydrate metabolism in normal humans. J Clin Invest 92:2283–2290, 1993 8227343
195 Andrews RC, Walker BR: Glucocorticoids and insulin resistance: old hormones, new targets. Clin Sci (Lond) 96:513–523, 1999 10209084
196 Tasali E, Chapotot F, Leproult R, Whitmore H, Ehrmann DA: Treatment of obstructive sleep apnea improves cardiometabolic function in young obese women with polycystic ovary syndrome. J Clin Endocrinol Metab 96:365–374, 2011 21123449
197 Lavie L, Lavie P: Molecular mechanisms of cardiovascular disease in OSAHS: the oxidative stress link. Eur Respir J 33:1467–1484, 2009 19483049
198 Lavie L: Oxidative stress—a unifying paradigm in obstructive sleep apnea and comorbidities. Prog Cardiovasc Dis 51:303–312, 2009 19110132
199 Barcelo A, Miralles C, Barbe F, Vila M, Pons S, Agusti AG: Abnormal lipid peroxidation in patients with sleep apnoea. Eur Respir J 16:644–647, 2000 11106206
200 Christou K, Markoulis N, Moulas AN, Pastaka C, Gourgoulianis KI: Reactive oxygen metabolites (ROMs) as an index of oxidative stress in obstructive sleep apnea patients. Sleep Breath 7:105–110, 2003 14569521
201 Lavie L, Vishnevsky A, Lavie P: Evidence for lipid peroxidation in obstructive sleep apnea. Sleep 27:123–128, 2004 14998248
202 Yamauchi M, Nakano H, Maekawa J, Okamoto Y, Ohnishi Y, Suzuki T, Kimura H: Oxidative stress in obstructive sleep apnea. Chest 127:1674–1679, 2005 15888845
203 Tan KC, Chow WS, Lam JC, Lam B, Wong WK, Tam S, Ip MS: HDL dysfunction in obstructive sleep apnea. Atherosclerosis 184:377–382, 2006 15975582
204 Christou K, Moulas AN, Pastaka C, Gourgoulianis KI: Antioxidant capacity in obstructive sleep apnea patients. Sleep Med 4:225–228, 2003 14592326
205 Jung HH, Han H, Lee JH: Sleep apnea, coronary artery disease, and antioxidant status in hemodialysis patients. Am J Kidney Dis 45:875–882, 2005 15861353
206 Dyugovskaya L, Lavie P, Lavie L: Increased adhesion molecules expression and production of reactive oxygen species in leukocytes of sleep apnea patients. Am J Respir Crit Care Med 165:934–939, 2002 11934717
207 Schulz R, Mahmoudi S, Hattar K, Sibelius U, Olschewski H, Mayer K, Seeger W, Grimminger F: Enhanced release of superoxide from polymorphonuclear neutrophils in obstructive sleep apnea. Impact of continuous positive airway pressure therapy. Am J Respir Crit Care Med 162:566–570, 2000 10934088
208 Saarelainen S, Lehtimaki T, Jaak-kola O, Poussa T, Nikkila M, Solakivi T, Nieminen MM: Autoantibodies against oxidised low-density lipoprotein in patients with obstructive sleep apnoea. Clin Chem Lab Med 37:517–520, 1999 10418741
209 Tiedge M, Lortz S, Drinkgern J, Lenzen S: Relation between antioxidant enzyme gene expression and antioxidative defense status of insulin-producing cells. Diabetes 46:1733–1742, 1997 9356019
210 Paolisso G, D’Amore A, Di Maro G, Galzerano D, Tesauro P, Varricchio M, D’Onofrio F: Evidence for a relationship between free radicals and insulin action in the elderly. Metabolism 42:659–663, 1993 8492724
211 Paolisso G, D’Amore A, Volpe C, Balbi V, Saccomanno F, Galzerano D, Giugliano D, Varricchio M, D’Onofrio F: Evidence for a relationship between oxidative stress and insulin action in non-insulin-dependent (type II) diabetic patients. Metabolism 43:1426–1429, 1994 7968598
212 Rudich A, Tirosh A, Potashnik R, Hemi R, Kanety H, Bashan N: Prolonged oxidative stress impairs insulin-induced GLUT4 translocation in 3T3-L1 adipocytes. Diabetes 47:1562–1569, 1998 9753293
213 Paolisso G, Di Maro G, Pizza G, D’Amore A, Sgambato S, Tesauro P, Varricchio M, D’Onofrio F: Plasma GSH/GSSG affects glucose homeostasis in healthy subjects and non-insulin-dependent diabetics. Am J Physiol 263:E435–E440, 1992 1415522
214 Caballero B: Vitamin E improves the action of insulin. Nutr Rev 51:339–340, 1993 8108035
215 Paolisso G, D’Amore A, Balbi V, Volpe C, Galzerano D, Giugliano D, Sgambato S, Varricchio M, D’Onofrio F: Plasma vitamin C affects glucose homeostasis in healthy subjects and in non-insulin-dependent diabetics. Am J Physiol 266:E261–E268, 1994 8141285
216 Jacob S, Ruus P, Hermann R, Tritschler HJ, Maerker E, Renn W, Augustin HJ, Dietze GJ, Rett K: Oral administration of RAC-alpha-lipoic acid modulates insulin sensitivity in patients with type-2 diabetes mellitus: a placebo-controlled pilot trial. Free Radic Biol Med 27:309–314, 1999 10468203
217 Ohga E, Nagase T, Tomita T, Teramoto S, Matsuse T, Katayama H, Ouchi Y: Increased levels of circulating ICAM-1, VCAM-1, and L-selectin in obstructive sleep apnea syndrome. J Appl Physiol 87:10–14, 1999 10409552
218 Chin K, Nakamura T, Shimizu K, Mishima M, Nakamura T, Miyasaka M, Ohi M: Effects of nasal continuous positive airway pressure on soluble cell adhesion molecules in patients with obstructive sleep apnea syndrome. Am J Med 109:562–567, 2000 11063958
219 El-Solh AA, Mador MJ, Sikka P, Dhillon RS, Amsterdam D, Grant BJ: Adhesion molecules in patients with coronary artery disease and moderate-to-severe obstructive sleep apnea. Chest 121:1541–1547, 2002 12006441
220 Ohga E, Tomita T, Wada H, Yamamoto H, Nagase T, Ouchi Y: Effects of obstructive sleep apnea on circulating ICAM-1, IL-8, and MCP-1. J Appl Physiol 94:179–184, 2003 12391099
221 O’Brien LM, Serpero LD, Tauman R, Gozal D: Plasma adhesion molecules in children with sleep-disordered breathing. Chest 129:947–953, 2006 16608943
222 Ursavas A, Karadag M, Rodoplu E, Yilmaztepe A, Oral HB, Gozu RO: Circulating ICAM-1 and VCAM-1 levels in patients with obstructive sleep apnea syndrome. Respiration 74:525–532, 2007 17148932
223 Alberti A, Sarchielli P, Gallinella E, Floridi A, Floridi A, Mazzotta G, Gallai V: Plasma cytokine levels in patients with obstructive sleep apnea syndrome: a preliminary study. J Sleep Res 12:305–311, 2003 14633242
224 Yokoe T, Minoguchi K, Matsuo H, Oda N, Minoguchi H, Yoshino G, Hirano T, Adachi M: Elevated levels of c-reactive protein and interleukin-6 in patients with obstructive sleep apnea syndrome are decreased by nasal continuous positive airway pressure. Circulation 107:1129–1134, 2003 12615790
225 Minoguchi K, Tazaki T, Yokoe T, Minoguchi H, Watanabe Y, Yamamoto M, Adachi M: Elevated production of tumor necrosis factor-alpha by monocytes in patients with obstructive sleep apnea syndrome. Chest 126:1473–1479, 2004 15539715
226 Ryan S, Taylor CT, McNicholas WT: Selective activation of inflammatory pathways by intermittent hypoxia in obstructive sleep apnea syndrome. Circulation 112:2660–2667, 2005 16246965
227 Dyugovskaya L, Lavie P, Hirsh M, Lavie L: Activated CD8+ T-lymphocytes in obstructive sleep apnoea. Eur Respir J 25:820–828, 2005 15863638
228 Dyugovskaya L, Lavie P, Lavie L: Phenotypic and functional characterization of blood gammadelta T cells in sleep apnea. Am J Respir Crit Care Med 168:242–249, 2003 12724124
229 Dyugovskaya L, Lavie P, Lavie L: Lymphocyte activation as a possible measure of atherosclerotic risk in patients with sleep apnea. Ann N Y Acad Sci 1051:340–350, 2005 16126976
230 Klokker M, Kharazmi A, Galbo H, Bygbjerg I, Pedersen BK: Influence of in vivo hypobaric hypoxia on function of lymphocytes, neutrocytes, natural killer cells, and cytokines. J Appl Physiol 74:1100–1106, 1993 8387070
231 Facco M, Zilli C, Siviero M, Ermolao A, Travain G, Baesso I, Bonamico S, Cabrelle A, Zaccaria M, Agostini C: Modulation of immune response by the acute and chronic exposure to high altitude. Med Sci Sports Exerc 37:768–774, 2005 15870630
232 Zhang Y, Hu Y, Wang F: Effects of a 28-day “living high—training low” on T-lymphocyte subsets in soccer players. Int J Sports Med 28:354–358, 2007 17024647
233 Madden KS, Sanders VM, Felten DL: Catecholamine influences and sympathetic neural modulation of immune responsiveness. Annu Rev Pharmacol Toxicol 35:417–448, 1995 7598501
234 Elenkov IJ, Wilder RL, Chrousos GP, Vizi ES: The sympathetic nerve—an integrative interface between two supersystems: the brain and the immune system. Pharmacol Rev 52:595–638, 2000 11121511
235 Punjabi NM, Beamer BA: C-reactive protein is associated with sleep disordered breathing independent of adiposity. Sleep 30:29–34, 2007 17310862
236 Ahima RS, Flier JS: Leptin. Annu Rev Physiol 62:413–437, 2000 10845097
237 Ceddia RB, Koistinen HA, Zierath JR, Sweeney G: Analysis of paradoxical observations on the association between leptin and insulin resistance. FASEB J 16:1163–1176, 2002 12153984
238 Margetic S, Gazzola C, Pegg GG, Hill RA: Leptin: a review of its peripheral actions and interactions. Int J Obes Relat Metab Disord 26:1407–1433, 2002 12439643
239 Ozturk L, Unal M, Tamer L, Celikoglu F: The association of the severity of obstructive sleep apnea with plasma leptin levels. Arch Otolaryngol Head Neck Surg 129:538–540, 2003 12759266
240 Patel SR, Palmer LJ, Larkin EK, Jenny NS, White DP, Redline S: Relationship between obstructive sleep apnea and diurnal leptin rhythms. Sleep 27:235–239, 2004 15124716
241 Shimura R, Tatsumi K, Nakamura A, Kasahara Y, Tanabe N, Takiguchi Y, Kuriyama T: Fat accumulation, leptin, and hypercapnia in obstructive sleep apnea-hypopnea syndrome. Chest 127:543–549, 2005 15705994
242 Tatsumi K, Kasahara Y, Kurosu K, Tanabe N, Takiguchi Y, Kuriyama T: Sleep oxygen desaturation and circulating leptin in obstructive sleep apnea-hypopnea syndrome. Chest 127:716–721, 2005 15764749
243 Ulukavak Ciftci T, Kokturk O, Bukan N, Bilgihan A: Leptin and ghrelin levels in patients with obstructive sleep apnea syndrome. Respiration 72:395–401, 2005 16088283
244 McArdle N, Hillman D, Beilin L, Watts G: Metabolic risk factors for vascular disease in obstructive sleep apnea: a matched controlled study. Am J Respir Crit Care Med 175:190–195, 2007 17068329
245 Sharma SK, Kumpawat S, Goel A, Banga A, Ramakrishnan L, Chaturvedi P: Obesity, and not obstructive sleep apnea, is responsible for metabolic abnormalities in a cohort with sleep-disordered breathing. Sleep Med 8:12–17, 2007 17157064
246 Saarelainen S, Lahtela J, Kallonen E: Effect of nasal CPAP treatment on insulin sensitivity and plasma leptin. J Sleep Res 6:146–147, 1997 9377535
247 Chin K, Shimizu K, Nakamura T, Narai N, Masuzaki H, Ogawa Y, Mishima M, Nakamura T, Nakao K, Ohi M: Changes in intra-abdominal visceral fat and serum leptin levels in patients with obstructive sleep apnea syndrome following nasal continuous positive airway pressure therapy. Circulation 100:706–712, 1999 10449691
248 Harsch IA, Konturek PC, Koebnick C, Kuehnlein PP, Fuchs FS, Pour Schahin S, Wiest GH, Hahn EG, Lohmann T, Ficker JH: Leptin and ghrelin levels in patients with obstructive sleep apnoea: effect of CPAP treatment. Eur Respir J 22:251–257, 2003 12952256
249 Sanner BM, Kollhosser P, Buechner N, Zidek W, Tepel M: Influence of treatment on leptin levels in patients with obstructive sleep apnoea. Eur Respir J 23:601–604, 2004 15083761
250 Tschop M, Strasburger CJ, Topfer M, Hautmann H, Riepl R, Fischer R, Hartmann G, Morrison K, Appenzeller M, Hildebrandt W, Biollaz J, Bartsch P: Influence of hypobaric hypoxia on leptin levels in men. Int J Obes Relat Metab Disord 24(Suppl 2):S151, 2000 10997640
251 Harsch IA, Wallaschofski H, Koebnick C, Pour Schahin S, Hahn EG, Ficker JH, Lohmann T: Adiponectin in patients with obstructive sleep apnea syndrome: course and physiological relevance. Respiration 71:580–586, 2004 15627868
252 Wolk R, Svatikova A, Nelson CA, Gami AS, Govender K, Winnicki M, Somers VK: Plasma levels of adiponectin, a novel adipocyte-derived hormone, in sleep apnea. Obes Res 13:186–190, 2005 15761179
253 Zhang XL, Yin KS, Mao H, Wang H, Yang Y: Serum adiponectin level in patients with obstructive sleep apnea hypopnea syndrome. Chin Med J (Engl) 117:1603–1606, 2004 15569472
254 Masserini B, Morpurgo PS, Donadio F, Baldessari C, Bossi R, Beck-Peccoz P, Orsi E: Reduced levels of adiponectin in sleep apnea syndrome. J Endocrinol Invest 29:700–705, 2006 17033258
255 Zhang XL, Yin KS, Wang H, Su S: Serum adiponectin levels in adult male patients with obstructive sleep apnea hypopnea syndrome. Respiration 73:73–77, 2006 16205042
256 Zhang XL, Yin KS, Li C, Jia EZ, Li YQ, Gao ZF: Effect of continuous positive airway pressure treatment on serum adiponectin level and mean arterial pressure in male patients with obstructive sleep apnea syndrome. Chin Med J (Engl) 120:1477–1481, 2007 17908452
257 Nakagawa Y, Kishida K, Kihara S, Sonoda M, Hirata A, Yasui A, Nishizawa H, Nakamura T, Yoshida R, Shimomura I, Funahashi T: Nocturnal reduction in circulating adiponectin concentrations related to hypoxic stress in severe obstructive sleep apnea-hypopnea syndrome. Am J Physiol Endocrinol Metab 294:E778–E784, 2008 18198351
258 Steppan CM, Bailey ST, Bhat S, Brown EJ, Banerjee RR, Wright CM, Patel HR, Ahima RS, Lazar MA: The hormone resistin links obesity to diabetes. Nature 409:307–312, 2001 11201732
259 Asano T, Sakosda H, Fujishiro M, Anai M, Kushiyama A, Horike N, Kamata H, Ogihara T, Kurihara H, Uchijima Y: Physiological significance of resistin and resistin-like molecules in the inflammatory process and insulin resistance. Curr Diabetes Rev 2:449–454, 2006 18220647
260 Harsch IA, Koebnick C, Wallaschofski H, Schahin SP, Hahn EG, Ficker JH, Lohmann T, Konturek PC: Resistin levels in patients with obstructive sleep apnoea syndrome—the link to subclinical inflammation? Med Sci Monit 10:CR510–CR515, 2004 15328483
261 Tauman R, Serpero LD, Capdevila OS, O’Brien LM, Goldbart AD, Kheirandish-Gozal L, Gozal D: Adipokines in children with sleep disordered breathing. Sleep 30:443–449, 2007 17520788
262 Lecube A, Sampol G, Lloberes P, Romero O, Mesa J, Hernandez C, Simo R: Diabetes is an independent risk factor for severe nocturnal hypoxemia in obese patients. A case-control study. PLOS ONE 4:e4692, 2009 19262746
263 Bottini P, Redolfi S, Dottorini ML, Tantucci C: Autonomic neuropathy increases the risk of obstructive sleep apnea in obese diabetics. Respiration 75:265–271, 2008 17347559
264 Keller T, Hader C, De Zeeuw J, Rasche K: Obstructive sleep apnea syndrome: the effect of diabetes and autonomic neuropathy. J Physiol Pharmacol 58(Suppl 5):313–318, 2007 18204141
265 Neumann C, Martinez D, Schmid H: Nocturnal oxygen desaturation in diabetic patients with severe autonomic neuropathy. Diabetes Res Clin Pract 28:97–102, 1995 7587925
266 Rees PJ, Prior JG, Cochrane GM, Clark TJ: Sleep apnoea in diabetic patients with autonomic neuropathy. J R Soc Med 74:192–195, 1981 7205856
267 Hein MS, Schlenker EH, Patel KP: Altered control of ventilation in streptozotocin-induced diabetic rats. Proc Soc Exp Biol Med 207:213–219, 1994 7938052
268 Tantucci C, Scionti L, Bottini P, Dottorini ML, Puxeddu E, Casucci G, Sorbini CA: Influence of autonomic neuropathy of different severities on the hypercapnic drive to breathing in diabetic patients. Chest 112:145–153, 1997 9228370
269 Kashine S, Kishida K, Funahashi T, Nakagawa Y, Otuki M, Okita K, Iwahashi H, Kihara S, Nakamura T, Matsuzawa Y, Shimomura I: Characteristics of sleep-disordered breathing in Japanese patients with type 2 diabetes mellitus. Metabolism 59:690–696, 2010 19913847
270 Noradina AT, Hamidon BB, Roslan H, Raymond AA: Risk factors for developing sleep-disordered breathing in patients with recent ischaemic stroke. Singapore Med J 47:392–399, 2006 16645689
271 Tada T, Kusano KF, Ogawa A, Iwasaki J, Sakuragi S, Kusano I, Takatsu S, Miyazaki M, Ohe T: The predictors of central and obstructive sleep apnoea in haemodialysis patients. Nephrol Dial Transplant 22:1190–1197, 2007 17277346
272 Pien GW, Schwab RJ: Sleep disorders during pregnancy. Sleep 27:1405–1417, 2004 15586794
273 Hedman C, Pohjasvaara T, Tolonen U, Suhonen-Malm AS, Myllyla VV: Effects of pregnancy on mothers’ sleep. Sleep Med 3:37–42, 2002 14592252
274 Lee KA, Zaffke ME, McEnany G: Parity and sleep patterns during and after pregnancy. Obstet Gynecol 95:14–18, 2000 10636494
275 Driver HS, Shapiro CM: A longitudinal study of sleep stages in young women during pregnancy and postpartum. Sleep 15:449–453, 1992 1455129
276 Hertz G, Fast A, Feinsilver SH, Albertario CL, Schulman H, Fein AM: Sleep in normal late pregnancy. Sleep 15:246–251, 1992 1621025
277 Mindell JA, Jacobson BJ: Sleep disturbances during pregnancy. J Obstet Gynecol Neonatal Nurs 29:590–597, 2000
278 O’Brien LM, Bullough AS, Owusu JT, Tremblay KA, Brincat CA, Chames MC, Kalbfleisch JD, Chervin RD: Pregnancy-onset habitual snoring, gestational hypertension, and preeclampsia: prospective cohort study. Am J Obstet Gynecol 207:487.e1–487.e9, 2012 22999158
279 Bourjeily G, Raker CA, Chalhoub M, Miller MA: Pregnancy and fetal outcomes of symptoms of sleep-disordered breathing. Eur Respir J 36:849–855, 2010 20525714
280 Maasilta P, Bachour A, Teramo K, Polo O, Laitinen LA: Sleep-related disordered breathing during pregnancy in obese women. Chest 120:1448–1454, 2001 11713118
281 Qiu C, Enquobahrie D, Frederick IO, Abetew D, Williams MA: Glucose intolerance and gestational diabetes risk in relation to sleep duration and snoring during pregnancy: a pilot study. BMC Womens Health 10:17, 2010 20470416
282 Facco FL, Grobman WA, Kramer J, Ho KH, Zee PC: Self-reported short sleep duration and frequent snoring in pregnancy: impact on glucose metabolism. Am J Obstet Gynecol 203:142.e1–142.e5, 2010 20510182
283 Ugur MG, Boynukalin K, Atak Z, Ustuner I, Atakan R, Baykal C: Sleep disturbances in pregnant patients and the relation to obstetric outcome. Clin Exp Obstet Gynecol 39:214–217, 2012 22905467
284 Reutrakul S, Zaidi N, Wroblewski K, Kay HH, Ismail M, Ehrmann DA, Van Cauter E: Sleep disturbances and their relationship to glucose tolerance in pregnancy. Diabetes Care 34:2454–2457, 2011 21926292
285 Bourjeily G, El Sabbagh R, Sawan P, Raker C, Wang C, Hott B, Louis M: Epworth sleepiness scale scores and adverse pregnancy outcomes. Sleep Breath 17:1179–1186, 2013 23420179
286 O’Brien LM, Bullough AS, Chames MC: Sleep duration and glucose levels in pregnant women (Abstract). Sleep 36(Suppl):A400, 2013
287 Facco FL, Liu CS, Cabello AA, Kick A, Gribman WA, Zee PC: Sleep-disordered breathing: a risk factor for adverse pregnancy outcomes? Am J Perinatol 29:277–282, 2012 22105436
288 Chen YH, Kang JH, Lin CC, Wang IT, Keller JJ, Lin HC: Obstructive sleep apnea and the risk of adverse pregnancy outcomes. Am J Obstet Gynecol 206:136.e1–136.e5, 2012 22000892
289 Izci Balserak B, Jackson N, Ratcliffe SA, Pack AI, Pien GW: Sleep-disordered breathing and daytime napping are associated with maternal hyperglycemia. Sleep Breath 17:1093–1102, 2013 23354511
290 Herring SJ, Nelson DB, Pien GW, Homko CJ, Goetzl L, Davey A, Foster GD: Objectively-measured sleep duration and hyperglycemia in pregnancy. Sleep Med 15:51–55, 2014 24239498
291 Facco FL, Ouyang D, Grobman W, Strohl A, Gonzalez A, Espinoza A, Verzillo V, Zee P: Sleep apnea is associated with an increased risk of gestational diabetes (Abstract). Sleep 36(Suppl):A123, 2013
292 Reutrakul S, Zaidi N, Wroblewski K, Kay HH, Ismail M, Ehrmann DA, Van Cauter E: Interactions between pregnancy, obstructive sleep apnea, and gestational diabetes mellitus. J Clin Endocrinol Metab 98:4195–4202, 2013 23966237
293 Bisson M, Series F, Giguere Y, Pamidi S, Kimoff J, Weisnagel SJ, Marc I: Gestational diabetes mellitus and sleep-disordered breathing. Obstet Gynecol 123:634–641, 2014 24499765
294 Luque-Fernandez MA, Bain PA, Gelaye B, Redline S, Williams MA: Sleep-disordered breathing and gestational diabetes mellitus: a meta-analysis of 9,795 participants enrolled in epidemiological observational studies. Diabetes Care 36:3353–3360, 2013 24065843
295 Louis JM, Auckley D, Sokol RJ, Mercer BM: Maternal and neonatal morbidities associated with obstructive sleep apnea complicating pregnancy. Am J Obstet Gynecol 202:261.e1–261.e5, 2010 20005507
296 Champagne K, Schwartzman K, Opatrny L, Barriga P, Morin L, Mallozzi A, Benjamin A, Kimoff RJ: Obstructive sleep apnoea and its association with gestational hypertension. Eur Respir J 33:559–565, 2009 19213789
297 August EM, Salihu HM, Biroscak BJ, Rahman S, Bruder K, Whiteman VE: Systematic review on sleep disorders and obstetric outcomes: scope of current knowledge. Am J Perinatol 30:323–334, 2013 22893551
298 Pamidi S, Pinto LM, Marc I, Benedetti A, Schwartzman K, Kimoff RJ: Maternal sleep-disordered breathing and adverse pregnancy outcomes: a systematic review and metaanalysis. Am J Obstet Gynecol 210:52.e1–52.e14, 2014 23911687
299 O’Keeffe M, St-Onge MP: Sleep duration and disorders in pregnancy: implications for glucose metabolism and pregnancy outcomes. Int J Obes (Lond) 37:765–770, 2013 22945608
300 Guilleminault C, Kreutzer M, Chang JL: Pregnancy, sleep disordered breathing and treatment with nasal continuous positive airway pressure. Sleep Med 5:43–51, 2004 14725826
301 Huang W, Ramsey KM, Marcheva B, Bass J: Circadian rhythms, sleep, and metabolism. J Clin Invest 121:2133–2141, 2011 21633182
302 Morris CJ, Yang JN, Scheer FA: The impact of the circadian timing system on cardiovascular and metabolic function. Prog Brain Res 199:337–358, 2012 22877674
303 Marcheva B, Ramsey KM, Peek CB, Affinati A, Maury E, Bass J: Circadian clocks and metabolism. Handb Exp Pharmacol 217:127–155, 2013
304 Turek FW, Joshu C, Kohsaka A, Lin E, Ivanova G, McDearmon E, Laposky A, Losee-Olson S, Easton A, Jensen DR, Eckel RH, Takahashi JS, Bass J: Obesity and metabolic syndrome in circadian Clock mutant mice. Science 308:1043–1045, 2005 15845877
305 Fonken LK, Workman JL, Walton JC, Weil ZM, Morris JS, Haim A, Nelson RJ: Light at night increases body mass by shifting the time of food intake. Proc Natl Acad Sci U S A 107:18664–18669, 2010 20937863
306 Bureau of Labor Statistics: Workers on Flexible and Shift Schedules in May 2004. Washington, DC: U.S. Department of Labor, Bureau of Labor Statistics, 2005
307 Oyama I, Kubo T, Fujino Y, Kadowaki K, Kunimoto M, Shirane K, Tabata H, Sabanai K, Nakamura T, Matsuda S: Retrospective cohort study of the risk of impaired glucose tolerance among shift workers. Scand J Work Environ Health 38:337–342, 2012 22508500
308 Suwazono Y, Uetani M, Oishi M, Tanaka K, Morimoto H, Sakata K: Calculation of the benchmark duration of shift work associated with the development of impaired glucose metabolism: a 14-year cohort study on 7104 male workers. Occup Environ Med 67:532–537, 2010 20573848
309 Eriksson AK, van den Donk M, Hilding A, Ostenson CG: Work stress, sense of coherence, and risk of type 2 diabetes in a prospective study of middle-aged Swedish men and women. Diabetes Care 36:2683–2689, 2013 23637356
310 Guo Y, Liu Y, Huang X, Rong Y, He M, Wang Y, Yuan J, Wu T, Chen W: The effects of shift work on sleeping quality, hypertension and diabetes in retired workers. PLOS ONE 8:e71107, 2013 23976988
311 Monk TH, Buysse DJ: Exposure to shift work as a risk factor for diabetes. J Biol Rhythms 28:356–359, 2013 24132061
312 Morikawa Y, Nakagawa H, Miura K, Soyama Y, Ishizaki M, Kido T, Naruse Y, Suwazono Y, Nogawa K: Shift work and the risk of diabetes mellitus among Japanese male factory workers. Scand J Work Environ Health 31:179–183, 2005 15999569
313 Oberlinner C, Ott MG, Nasterlack M, Yong M, Messerer P, Zober A, Lang S: Medical program for shift workers—impacts on chronic disease and mortality outcomes. Scand J Work Environ Health 35:309–318, 2009 19471844
314 Pan A, Schernhammer ES, Sun Q, Hu FB: Rotating night shift work and risk of type 2 diabetes: two prospective cohort studies in women. PLOS Med 8:e1001141, 2011 22162955
315 Suwazono Y, Sakata K, Okubo Y, Harada H, Oishi M, Kobayashi E, Uetani M, Kido T, Nogawa K: Long-term longitudinal study on the relationship between alternating shift work and the onset of diabetes mellitus in male Japanese workers. J Occup Environ Med 48:455–461, 2006 16688001
316 Teratani T, Morimoto H, Sakata K, Oishi M, Tanaka K, Nakada S, Nogawa K, Suwazono Y: Dose-response relationship between tobacco or alcohol consumption and the development of diabetes mellitus in Japanese male workers. Drug Alcohol Depend 125:276–282, 2012 22445622
317 Poulsen K, Cleal B, Clausen T, Andersen LL: Work, diabetes and obesity: a seven year follow-up study among Danish health care workers. PLOS ONE 9:e103425, 2014 25068830
318 Vimalananda VG, Palmer JR, Gerlovin H, Wise LA, Rosenzweig JL, Rosenberg L, Ruiz Narvaez EA: Night-shift work and incident diabetes among African-American women. Diabetologia 58:699–706, 2015 25586362
319 Morikawa Y, Miura K, Sasaki S, Yoshita K, Yoneyama S, Sakurai M, Ishizaki M, Kido T, Naruse Y, Suwazono Y, Higashiyama M, Nakagawa H: Evaluation of the effects of shift work on nutrient intake: a cross-sectional study. J Occup Health 50:270–278, 2008 18408349
320 Lennernas M, Hambraeus L, Akerstedt T: Shift related dietary intake in day and shift workers. Appetite 25:253–265, 1995 8746965
321 de Assis MA, Nahas MV, Bellisle F, Kupek E: Meals, snacks and food choices in Brazilian shift workers with high energy expenditure. J Hum Nutr Diet 16:283–289, 2003 12859710
322 Gan Y, Yang C, Tong X, Sun H, Cong Y, Yin X, Li L, Cao S, Dong X, Gong Y, Shi O, Deng J, Bi H, Lu Z: Shift work and diabetes mellitus: a meta-analysis of observational studies. Occup Environ Med 72:72–78, 2015 25030030
323 Anothaisintawee T, Reutrakul S, Van Cauter E, Thakkinstian A: Sleep disturbances compared to traditional risk factors for diabetes development: systematic review and meta-analysis. Sleep Med Rev 30:11–24, 2015 26687279
324 Scheer FA, Hilton MF, Mantzoros CS, Shea SA: Adverse metabolic and cardiovascular consequences of circadian misalignment. Proc Natl Acad Sci U S A 106:4453–4458, 2009 19255424
325 Buxton OM, Cain SW, O’Connor SP, Porter JH, Duffy JF, Wang W, Czeisler CA, Shea SA: Adverse metabolic consequences in humans of prolonged sleep restriction combined with circadian disruption. Sci Transl Med 4:129ra43, 2012
326 McHill AW, Melanson EL, Higgins J, Connick E, Moehlman TM, Stothard ER, Wright KP, Jr.: Impact of circadian misalignment on energy metabolism during simulated nightshift work. Proc Natl Acad Sci U S A 111:17302–17307, 2014 25404342
327 Morris CJ, Yang JN, Garcia JI, Myers S, Bozzi I, Wang W, Buxton OM, Shea SA, Scheer FA: Endogenous circadian system and circadian misalignment impact glucose tolerance via separate mechanisms in humans. Proc Natl Acad Sci U S A 112:E2225–E2234, 2015 25870289
328 Poole CJ, Wright AD, Nattrass M: Control of diabetes mellitus in shift workers. Br J Ind Med 49:513–515, 1992 1637712
329 Chalernvanichakorn T, Sithisarankul P, Hiransuthikul N: Shift work and type 2 diabetic patients’ health. J Med Assoc Thai 91:1093–1096, 2008 18839851
330 Young J, Waclawski E, Young JA, Spencer J: Control of type 1 diabetes mellitus and shift work. Occup Med (Lond) 63:70–72, 2013 23024256
331 Zee PC, Attarian H, Videnovic A: Circadian rhythm abnormalities. Continuum (Minneap Minn) 19:132–147, 2013 23385698
332 Kantermann T, Duboutay F, Haubruge D, Hampton S, Darling AL, Berry JL, Kerkhofs M, Boudjeltia KZ, Skene DJ: The direction of shift-work rotation impacts metabolic risk independent of chronotype and social jetlag—an exploratory pilot study. Chronobiol Int 31:1139–1145, 2014 25187988
333 Wittmann M, Dinich J, Merrow M, Roenneberg T: Social jetlag: misalignment of biological and social time. Chronobiol Int 23:497–509, 2006 16687322
334 Horne JA, Ostberg O: A self-assessment questionnaire to determine morningness-eveningness in human circadian rhythms. Int J Chronobiol 4:97–110, 1976 1027738
335 Roenneberg T, Kuehnle T, Juda M, Kantermann T, Allebrandt K, Gordijn M, Merrow M: Epidemiology of the human circadian clock. Sleep Med Rev 11:429–438, 2007 17936039
336 Roenneberg T, Kuehnle T, Pramstaller PP, Ricken J, Havel M, Guth A, Merrow M: A marker for the end of adolescence. Curr Biol 14:R1038–R1039, 2004 15620633
337 Merikanto I, Lahti T, Puolijoki H, Vanhala M, Peltonen M, Laatikainen T, Vartiainen E, Salomaa V, Kronholm E, Partonen T: Associations of chronotype and sleep with cardiovascular diseases and type 2 diabetes. Chronobiol Int 30:470–477, 2013 23281716
338 Wong PM, Roecklein KA, Muldoon M, Manuck S: Later chronotype is associated with increased risk for the metabolic syndrome (Abstract). Sleep 36(Suppl):A285, 2013
339 Finn L, Young EJ, Mignot E, Young T, Peppard PE: Associations of eveningness chronotype with adverse metabolic indications in the Wisconsin Sleep Cohort (Abstract). Sleep 36(Suppl):A188, 2013
340 Garaulet M, Esteban Tardido A, Lee YC, Smith CE, Parnell LD, Ordovas JM: SIRT1 and CLOCK 3111T>C combined genotype is associated with evening preference and weight loss resistance in a behavioral therapy treatment for obesity. Int J Obes (Lond) 36:1436–1441, 2012 22310473
341 Scott EM, Carter AM, Grant PJ: Association between polymorphisms in the Clock gene, obesity and the metabolic syndrome in man. Int J Obes (Lond) 32:658–662, 2008 18071340
342 Woon PY, Kaisaki PJ, Braganca J, Bihoreau MT, Levy JC, Farrall M, Gauguier D: Aryl hydrocarbon receptor nuclear translocator-like (BMAL1) is associated with susceptibility to hypertension and type 2 diabetes. Proc Natl Acad Sci U S A 104:14412–14417, 2007 17728404
343 Lucassen EA, Zhao X, Rother KI, Mattingly MS, Courville AB, de Jonge L, Csako G, Cizza G; Sleep Extension Study Group: Evening chronotype is associated with changes in eating behavior, more sleep apnea, and increased stress hormones in short sleeping obese individuals. PLOS ONE 8:e56519, 2013 23483886
344 Reutrakul S, Hood MM, Crowley SJ, Morgan MK, Teodori M, Knutson KL, Van Cauter E: Chronotype is independently associated with glycemic control in type 2 diabetes. Diabetes Care 36:2523–2529, 2013 23637357
345 Iwasaki M, Hirose T, Mita T, Sato F, Ito C, Yamamoto R, Someya Y, Yoshihara T, Tamura Y, Kanazawa A, Kawamori R, Fujitani Y, Watada H: Morningness-eveningness questionnaire score correlates with glycated hemoglobin in middle-aged male workers with type 2 diabetes mellitus. J Diabetes Investig 4:376–381, 2013
346 Osonoi Y, Mita T, Osonoi T, Saito M, Tamasawa A, Nakayama S, Someya Y, Ishida H, Kanazawa A, Gosho M, Fujitani Y, Watada H: Morningness-eveningness questionnaire score and metabolic parameters in patients with type 2 diabetes mellitus. Chronobiol Int 31:1017–1023, 2014 25102425
347 Brzezinski A: Melatonin in humans. N Engl J Med 336:186–195, 1997 8988899
348 Waldhauser F, Dietzel M: Daily and annual rhythms in human melatonin secretion: role in puberty control. Ann N Y Acad Sci 453:205–214, 1985 3865581
349 Crowley SJ: Assessment of circadian rhythms. In The Oxford Handbook of Infant, Child, and Adolescent Sleep and Behavior. Wolfson AR, Montgomery-Downs HE, Eds. New York, NY, Oxford University Press, 2013, p. 204–222
350 Peschke E, Muhlbauer E: New evidence for a role of melatonin in glucose regulation. Best Pract Res Clin Endocrinol Metab 24:829–841, 2010 21112029
351 Slominski RM, Reiter RJ, Schlabritz-Loutsevitch N, Ostrom RS, Slominski AT: Melatonin membrane receptors in peripheral tissues: distribution and functions. Mol Cell Endocrinol 351:152–166, 2012 22245784
352 McArthur AJ, Gillette MU, Prosser RA: Melatonin directly resets the rat suprachiasmatic circadian clock in vitro. Brain Res 565:158–161, 1991 1773352
353 Ramracheya RD, Muller DS, Squires PE, Brereton H, Sugden D, Huang GC, Amiel SA, Jones PM, Persaud SJ: Function and expression of melatonin receptors on human pancreatic islets. J Pineal Res 44:273–279, 2008 18194202
354 Cizza G, Requena M, Galli G, de Jonge L: Chronic sleep deprivation and seasonality: implications for the obesity epidemic. J Endocrinol Invest 34:793–800, 2011 21720205
355 Sparso T, Bonnefond A, Andersson E, Bouatia-Naji N, Holmkvist J, Wegner L, Grarup N, Gjesing AP, Banasik K, Cavalcanti-Proenca C, Marchand M, Vaxillaire M, Charpentier G, Jarvelin MR, Tichet J, Balkau B, Marre M, Levy-Marchal C, Faerch K, Borch-Johnsen K, Jorgensen T, Madsbad S, Poulsen P, Vaag A, Dina C, Hansen T, Pedersen O, Froguel P: G-allele of intronic rs10830963 in MTNR1B confers increased risk of impaired fasting glycemia and type 2 diabetes through an impaired glucose-stimulated insulin release: studies involving 19,605 Europeans. Diabetes 58:1450–1456, 2009 19324940
356 Langenberg C, Pascoe L, Mari A, Tura A, Laakso M, Frayling TM, Barroso I, Loos RJ, Wareham NJ, Walker M; RISC Consortium: Common genetic variation in the melatonin receptor 1B gene (MTNR1B) is associated with decreased early-phase insulin response. Diabetologia 52:1537–1542, 2009 19455304
357 Prokopenko I, Langenberg C, Florez JC, Saxena R, Soranzo N, Thorleifsson G, Loos RJ, Manning AK, Jackson AU, Aulchenko Y, Potter SC, Erdos MR, Sanna S, Hottenga JJ, Wheeler E, Kaakinen M, Lyssenko V, Chen WM, Ahmadi K, Beckmann JS, Bergman RN, Bochud M, Bonnycastle LL, Buchanan TA, Cao A, Cervino A, Coin L, Collins FS, Crisponi L, de Geus EJ, Dehghan A, Deloukas P, Doney AS, Elliott P, Freimer N, Gateva V, Herder C, Hofman A, Hughes TE, Hunt S, Illig T, Inouye M, Isomaa B, Johnson T, Kong A, Krestyaninova M, Kuusisto J, Laakso M, Lim N, Lindblad U, Lindgren CM, McCann OT, Mohlke KL, Morris AD, Naitza S, Orru M, Palmer CN, Pouta A, Randall J, Rathmann W, Saramies J, Scheet P, Scott LJ, Scuteri A, Sharp S, Sijbrands E, Smit JH, Song K, Steinthorsdottir V, Stringham HM, Tuomi T, Tuomilehto J, Uitterlinden AG, Voight BF, Waterworth D, Wichmann HE, Willemsen G, Witteman JC, Yuan X, Zhao JH, Zeggini E, Schlessinger D, Sandhu M, Boomsma DI, Uda M, Spector TD, Penninx BW, Altshuler D, Vollenweider P, Jarvelin MR, Lakatta E, Waeber G, Fox CS, Peltonen L, Groop LC, Mooser V, Cupples LA, Thorsteinsdottir U, Boehnke M, Barroso I, Van Duijn C, Dupuis J, Watanabe RM, Stefansson K, McCarthy MI, Wareham NJ, Meigs JB, Abecasis GR: Variants in MTNR1B influence fasting glucose levels. Nat Genet 41:77–81, 2009 19060907
358 Lyssenko V, Nagorny CL, Erdos MR, Wierup N, Jonsson A, Spegel P, Bugliani M, Saxena R, Fex M, Pulizzi N, Isomaa B, Tuomi T, Nilsson P, Kuusisto J, Tuomilehto J, Boehnke M, Altshuler D, Sundler F, Eriksson JG, Jackson AU, Laakso M, Marchetti P, Watanabe RM, Mulder H, Groop L: Common variant in MTNR1B associated with increased risk of type 2 diabetes and impaired early insulin secretion. Nat Genet 41:82–88, 2009 19060908
359 Bonnefond A, Clement N, Fawcett K, Yengo L, Vaillant E, Guillaume JL, Dechaume A, Payne F, Roussel R, Czernichow S, Hercberg S, Hadjadj S, Balkau B, Marre M, Lantieri O, Langenberg C, Bouatia-Naji N; Meta-Analysis of Glucose and Insulin-Related Traits Consortium (MAGIC), Charpentier G, Vaxillaire M, Rocheleau G, Wareham NJ, Sladek R, McCarthy MI, Dina C, Barroso I, Jockers R, Froguel P: Rare MTNR1B variants impairing melatonin receptor 1B function contribute to type 2 diabetes. Nat Genet 44:297–301, 2012 22286214
360 McMullan CJ, Schernhammer ES, Rimm EB, Hu FB, Forman JP: Melatonin secretion and the incidence of type 2 diabetes. JAMA 309:1388–1396, 2013 23549584
361 Diethelm K, Libuda L, Bolzenius K, Griefahn B, Buyken AE, Remer T: Longitudinal associations between endogenous melatonin production and reported sleep duration from childhood to early adulthood. Horm Res Paediatr 74:390–398, 2010 20516653
362 Hernandez C, Abreu J, Abreu P, Castro A, Jimenez A: Nocturnal melatonin plasma levels in patients with OSAS: the effect of CPAP. Eur Respir J 30:496–500, 2007 17537771
363 Garfinkel D, Zorin M, Wainstein J, Matas Z, Laudon M, Zisapel N: Efficacy and safety of prolonged-release melatonin in insomnia patients with diabetes: a randomized, double-blind, crossover study. Diabetes Metab Syndr Obes 4:307–313, 2011 21887103
364 Rubio-Sastre P, Scheer FA, Gomez-Abellan P, Madrid JA, Garaulet M: Acute melatonin administration in humans impairs glucose tolerance in both the morning and evening. Sleep 37:1715–1719, 2014 25197811
365 Vasisht KP, Kessler LE, Booth JN, 3rd, Imperial JG, Penev PD: Differences in insulin secretion and sensitivity in short-sleep insomnia. Sleep 36:955–957, 2013 23729940
366 Vgontzas AN, Liao D, Pejovic S, Calhoun S, Karataraki M, Basta M, Fernandez-Mendoza J, Bixler EO: Insomnia with short sleep duration and mortality: the Penn State cohort. Sleep 33:1159–1164, 2010 20857861
367 Cespedes EM, Dudley KA, Sotres-Alvarez D, Zee PC, Daviglus ML, Shah NA, Talavera GA, Gallo LC, Mattei J, Qi Q, Ramos AR, Schneiderman N, Espinoza-Giacinto RA, Patel SR: Joint associations of insomnia and sleep duration with prevalent diabetes: the Hispanic Community Health Study/Study of Latinos (HCHS/SOL). J Diabetes 8:387–397, 2016 25952169
368 Kim NH, Lee SK, Eun CR, Seo JA, Kim SG, Choi KM, Baik SH, Choi DS, Yun CH, Kim NH, Shin C: Short sleep duration combined with obstructive sleep apnea is associated with visceral obesity in Korean adults. Sleep 36:723–729, 2013 23633755
369 Chin K, Oga T, Takahashi K, Takegami M, Nakayama-Ashida Y, Wakamura T, Sumi K, Nakamura T, Horita S, Oka Y, Minami I, Fukuhara S, Kadotani H: Associations between obstructive sleep apnea, metabolic syndrome, and sleep duration, as measured with an actigraph, in an urban male working population in Japan. Sleep 33:89–95, 2010 20120625
370 Siwasaranond N, Nimitphong H, Saetung S, Chirakalwasan N, Ongphiphadhanakul B, Reutrakul S: Shorter sleep duration is associated with poorer glycemic control in type 2 diabetes patients with untreated sleep-disordered breathing. Sleep Breath 20:569–574, 2016 26298194
371 Lajoie P, Aronson KJ, Day A, Tranmer J: A cross-sectional study of shift work, sleep quality and cardiometabolic risk in female hospital employees. BMJ Open 5:e007327, 2015
372 Laudencka A, Klawe JJ, Tafil-Klawe M, Zlomanczuk P: Does night-shift work induce apnea events in obstructive sleep apnea patients? J Physiol Pharmacol 58(Suppl 5):345–347, 2007 18204146
373 Paciorek M, Korczynski P, Bielicki P, Byskiniewicz K, Zielinski J, Chazan R: Obstructive sleep apnea in shift workers. Sleep Med 12:274–277, 2011 21316298
374 Gottlieb DJ, Punjabi NM, Newman AB, Resnick HE, Redline S, Baldwin CM, Nieto FJ: Association of sleep time with diabetes mellitus and impaired glucose tolerance. Arch Intern Med 165:863–867, 2005 15851636
375 Rafalson L, Donahue RP, Stranges S, Lamonte MJ, Dmochowski J, Dorn J, Trevisan M: Short sleep duration is associated with the development of impaired fasting glucose: the Western New York Health Study. Ann Epidemiol 20:883–889, 2010 20620078
376 Grandner MA, Chakravorty S, Perlis ML, Oliver L, Gurubhagavatula I: Habitual sleep duration associated with self-reported and objectively determined cardiometabolic risk factors. Sleep Med 15:42–50, 2014 24333222
377 Jackson CL, Redline S, Kawachi I, Hu FB: Association between sleep duration and diabetes in black and white adults. Diabetes Care 36:3557–3565, 2013 24026552
378 Liu Y, Wheaton AG, Chapman DP, Croft JB: Sleep duration and chronic diseases among U.S. adults age 45 years and older: evidence from the 2010 Behavioral Risk Factor Surveillance System. Sleep 36:1421–1427, 2013 24082301
379 Zizi F, Pandey A, Murrray-Bachmann R, Vincent M, McFarlane S, Ogedegbe G, Jean-Louis G: Race/ethnicity, sleep duration, and diabetes mellitus: analysis of the National Health Interview Survey. Am J Med 125:162–167, 2012 22269619
380 Young T, Palta M, Dempsey J, Skatrud J, Weber S, Badr S: The occurrence of sleep-disordered breathing among middle-aged adults. N Engl J Med 328:1230–1235, 1993 8464434
381 Bixler EO, Vgontzas AN, Ten Have T, Tyson K, Kales A: Effects of age on sleep apnea in men: I. prevalence and severity. Am J Respir Crit Care Med 157:144–148, 1998 9445292
382 Bixler EO, Vgontzas AN, Lin HM, Ten Have T, Rein J, Vela-Bueno A, Kales A: Prevalence of sleep-disordered breathing in women: effects of gender. Am J Respir Crit Care Med 163:608–613, 2001 11254512
383 Bearpark H, Elliott L, Grunstein R, Cullen S, Schneider H, Althaus W, Sullivan C: Snoring and sleep apnea. A population study in Australian men. Am J Respir Crit Care Med 151:1459–1465, 1995 7735600
384 Udwadia ZF, Doshi AV, Lonkar SG, Singh CI: Prevalence of sleep-disordered breathing and sleep apnea in middle-aged urban Indian men. Am J Respir Crit Care Med 169:168–173, 2004 14604837
385 Ip MS, Lam B, Lauder IJ, Tsang KW, Chung KF, Mok YW, Lam WK: A community study of sleep-disordered breathing in middle-aged Chinese men in Hong Kong. Chest 119:62–69, 2001 11157585
386 Ip MS, Lam B, Tang LC, Lauder IJ, Ip TY, Lam WK: A community study of sleep-disordered breathing in middle-aged Chinese women in Hong Kong: prevalence and gender differences. Chest 125:127–134, 2004 14718431
387 Kim J, In K, Kim J, You S, Kang K, Shim J, Lee S, Lee J, Lee S, Park C, Shin C: Prevalence of sleep-disordered breathing in middle-aged Korean men and women. Am J Respir Crit Care Med 170:1108–1113, 2004 15347562
388 Tiihonen M, Partinen M, Narvanen S: The severity of obstructive sleep apnoea is associated with insulin resistance. J Sleep Res 2:56–61, 1993 10607072
389 Strohl KP, Novak RD, Singer W, Cahan C, Boehm KD, Denko CW, Hoffstem VS: Insulin levels, blood pressure and sleep apnea. Sleep 17:614–618, 1994 7846459
390 Davies RJ, Turner R, Crosby J, Stradling JR: Plasma insulin and lipid levels in untreated obstructive sleep apnoea and snoring; their comparison with matched controls and response to treatment. J Sleep Res 3:180–185, 1994 10607124
391 Grunstein RR, Stenlof K, Hedner J, Sjostrom L: Impact of obstructive sleep apnea and sleepiness on metabolic and cardiovascular risk factors in the Swedish Obese Subjects (SOS) Study. Int J Obes Relat Metab Disord 19:410–418, 1995 7550526
392 Stoohs RA, Facchini F, Guilleminault C: Insulin resistance and sleep-disordered breathing in healthy humans. Am J Respir Crit Care Med 154:170–174, 1996 8680675
393 Ip MS, Lam KS, Ho C, Tsang KW, Lam W: Serum leptin and vascular risk factors in obstructive sleep apnea. Chest 118:580–586, 2000 10988175
394 Vgontzas AN, Papanicolaou DA, Bixler EO, Hopper K, Lotsikas A, Lin HM, Kales A, Chrousos GP: Sleep apnea and daytime sleepiness and fatigue: relation to visceral obesity, insulin resistance, and hypercytokinemia. J Clin Endocrinol Metab 85:1151–1158, 2000 10720054
395 Elmasry A, Lindberg E, Berne C, Janson C, Gislason T, Awad Tageldin M, Boman G: Sleep-disordered breathing and glucose metabolism in hypertensive men: a population-based study. J Intern Med 249:153–161, 2001 11240844
396 Ip MS, Lam B, Ng MM, Lam WK, Tsang KW, Lam KS: Obstructive sleep apnea is independently associated with insulin resistance. Am J Respir Crit Care Med 165:670–676, 2002 11874812
397 Manzella D, Parillo M, Razzino T, Gnasso P, Buonanno S, Gargiulo A, Caputi M, Paolisso G: Soluble leptin receptor and insulin resistance as determinant of sleep apnea. Int J Obes Relat Metab Disord 26:370–375, 2002 11896492
398 Punjabi NM, Sorkin JD, Katzel LI, Goldberg AP, Schwartz AR, Smith PL: Sleep-disordered breathing and insulin resistance in middle-aged and overweight men. Am J Respir Crit Care Med 165:677–682, 2002 11874813
399 Meslier N, Gagnadoux F, Giraud P, Person C, Ouksel H, Urban T, Racineux JL: Impaired glucose-insulin metabolism in males with obstructive sleep apnoea syndrome. Eur Respir J 22:156–160, 2003 12882466
400 Tassone F, Lanfranco F, Gianotti L, Pivetti S, Navone F, Rossetto R, Grottoli S, Gai V, Ghigo E, Maccario M: Obstructive sleep apnoea syndrome impairs insulin sensitivity independently of anthropometric variables. Clin Endocrinol (Oxf) 59:374–379, 2003 12919162
401 Barcelo A, Barbe F, Llompart E, Mayoralas LR, Ladaria A, Bosch M, Agusti AG: Effects of obesity on c-reactive protein level and metabolic disturbances in male patients with obstructive sleep apnea. Am J Med 117:118–121, 2004 15234648
402 Makino S, Handa H, Suzukawa K, Fujiwara M, Nakamura M, Muraoka S, Takasago I, Tanaka Y, Hashimoto K, Sugimoto T: Obstructive sleep apnoea syndrome, plasma adiponectin levels, and insulin resistance. Clin Endocrinol (Oxf) 64:12–19, 2006 16402923
403 Kapsimalis F, Varouchakis G, Manousaki A, Daskas S, Nikita D, Kryger M, Gourgoulianis K: Association of sleep apnea severity and obesity with insulin resistance, c-reactive protein, and leptin levels in male patients with obstructive sleep apnea. Lung 186:209–217, 2008 18365276
404 Theorell-Haglow J, Berne C, Janson C, Lindberg E: Obstructive sleep apnoea is associated with decreased insulin sensitivity in females. Eur Respir J 31:1054–1060, 2008 18184681
405 Tkacova R, Dorkova Z, Molcanyiova A, Radikova Z, Klimes I, Tkac I: Cardiovascular risk and insulin resistance in patients with obstructive sleep apnea. Med Sci Monit 14:CR438–CR444, 2008 18758413
406 Punjabi NM, Beamer BA: Alterations in glucose disposal in sleep-disordered breathing. Am J Respir Crit Care Med 179:235–240, 2009 19011148
407 Kelly A, Dougherty S, Cucchiara A, Marcus CL, Brooks LJ: Catecholamines, adiponectin, and insulin resistance as measured by HOMA in children with obstructive sleep apnea. Sleep 33:1185–1191, 2010 20857865
408 Deboer MD, Mendoza JP, Liu L, Ford G, Yu PL, Gaston BM: Increased systemic inflammation overnight correlates with insulin resistance among children evaluated for obstructive sleep apnea. Sleep Breath 16:349–354, 2012 21360253
409 Seicean S, Kirchner HL, Gottlieb DJ, Punjabi NM, Resnick H, Sanders M, Budhiraja R, Singer M, Redline S: Sleep-disordered breathing and impaired glucose metabolism in normal-weight and overweight/obese individuals: the Sleep Heart Health Study. Diabetes Care 31:1001–1006, 2008 18268072
410 Tuomilehto H, Peltonen M, Partinen M, Seppa J, Saaristo T, Korpi-Hyovalti E, Oksa H, Puolijoki H, Saltevo J, Vanhala M, Tuomilehto J: Sleep duration is associated with an increased risk for the prevalence of type 2 diabetes in middle-aged women—the FIN-D2D survey. Sleep Med 9:221–227, 2008 17644479
411 Al-Delaimy WK, Manson JE, Willett WC, Stampfer MJ, Hu FB: Snoring as a risk factor for type II diabetes mellitus: a prospective study. Am J Epidemiol 155:387–393, 2002 11867347
412 Leineweber C, Kecklund G, Akerstedt T, Janszky I, Orth-Gomer K: Snoring and the metabolic syndrome in women. Sleep Med 4:531–536, 2003 14607347
413 Coughlin SR, Mawdsley L, Mugarza JA, Calverley PM, Wilding JP: Obstructive sleep apnoea is independently associated with an increased prevalence of metabolic syndrome. Eur Heart J 25:735–741, 2004 15120883
414 Dursunoglu N, Dursunoglu D, Ozkurt S, Kiter G, Evyapan F: Gender differences in global cardiovascular risk factors of obstructive sleep apnea patients. Tuberk Toraks 54:305–314, 2006 17203415
415 Sasanabe R, Banno K, Otake K, Hasegawa R, Usui K, Morita M, Shiomi T: Metabolic syndrome in Japanese patients with obstructive sleep apnea syndrome. Hypertens Res 29:315–322, 2006 16832151
416 Gruber A, Horwood F, Sithole J, Ali NJ, Idris I: Obstructive sleep apnoea is independently associated with the metabolic syndrome but not insulin resistance state. Cardiovasc Diabetol 5:22, 2006 17078884
417 Lam JC, Lam B, Lam CL, Fong D, Wang JK, Tse HF, Lam KS, Ip MS: Obstructive sleep apnea and the metabolic syndrome in community-based Chinese adults in Hong Kong. Respir Med 100:980–987, 2006 16337115
418 Onat A, Hergenc G, Uyarel H, Yazici M, Tuncer M, Dogan Y, Can G, Rasche K: Obstructive sleep apnea syndrome is associated with metabolic syndrome rather than insulin resistance. Sleep Breath 11:23–30, 2007 17061139
419 Peled N, Kassirer M, Shitrit D, Kogan Y, Shlomi D, Berliner AS, Kramer MR: The association of OSA with insulin resistance, inflammation and metabolic syndrome. Respir Med 101:1696–1701, 2007 17466499
420 Kono M, Tatsumi K, Saibara T, Nakamura A, Tanabe N, Takiguchi Y, Kuriyama T: Obstructive sleep apnea syndrome is associated with some components of metabolic syndrome. Chest 131:1387–1392, 2007 17494788
421 Parish JM, Adam T, Facchiano L: Relationship of metabolic syndrome and obstructive sleep apnea. J Clin Sleep Med 3:467–472, 2007 17803009
422 Katsumata K, Okada T, Miyao M, Katsumata Y: High incidence of sleep apnea syndrome in a male diabetic population. Diabetes Res Clin Pract 13:45–51, 1991 1773713
423 Renko AK, Hiltunen L, Laakso M, Rajala U, Keinanen-Kiukaanniemi S: The relationship of glucose tolerance to sleep disorders and daytime sleepiness. Diabetes Res Clin Pract 67:84–91, 2005 15620438
424 West SD, Nicoll DJ, Stradling JR: Prevalence of obstructive sleep apnoea in men with type 2 diabetes. Thorax 61:945–950, 2006 16928713
425 Juuti AK, Hiltunen L, Rajala U, Laakso M, Harkonen P, Hedberg P, Ruokonen A, Keinanen-Kiukaanniemi S, Laara E: Association of abnormal glucose tolerance with self-reported sleep apnea among a 57-year-old urban population in Northern Finland. Diabetes Res Clin Pract 80:477–482, 2008 18353486
426 Venkateswaran S, Shankar P: The prevalence of syndrome Z (the interaction of obstructive sleep apnoea with the metabolic syndrome) in a teaching hospital in Singapore. Postgrad Med J 83:329–331, 2007 17488863
427 Takama N, Kurabayashi M: Relationship between metabolic syndrome and sleep-disordered breathing in patients with cardiovascular disease—metabolic syndrome as a strong factor of nocturnal desaturation. Intern Med 47:709–715, 2008 18421186
428 Mikuni E, Ohoshi T, Hayashi K, Miyamura K: Glucose intolerance in an employed population. Tohoku J Exp Med 141(Suppl):251–256, 1983 6680494
429 Nagaya T, Yoshida H, Takahashi H, Kawai M: Markers of insulin resistance in day and shift workers aged 30–59 years. Int Arch Occup Environ Health 75:562–568, 2002 12373318
430 Karlsson BH, Knutsson AK, Lindahl BO, Alfredsson LS: Metabolic disturbances in male workers with rotating three-shift work. Results of the WOLF study. Int Arch Occup Environ Health 76:424–430, 2003 12783235
431 Ika K, Suzuki E, Mitsuhashi T, Takao S, Doi H: Shift work and diabetes mellitus among male workers in Japan: does the intensity of shift work matter? Acta Med Okayama 67:25–33, 2013 23439506