# CHAPTER 24 Diabetes and Cognitive Impairment

## Summary

Cognitive impairment, ranging from mild cognitive impairment to dementia, is increasingly recognized as a potential complication of diabetes. The increase in the prevalence of diabetes along with the aging of the population may result in a large increase in the prevalence of cognitive impairment in persons with diabetes. Approximately one-third of the United States adult population has prediabetes or diabetes. However, about one-half of persons age ≥60 years, who are most at risk for cognitive impairment, have prediabetes or diabetes. The association of diabetes and cognitive impairment may reflect a direct effect on the brain of hyperglycemia or the effects of the diabetes-associated comorbidities, such as hypertension, dyslipidemia, or hyperinsulinemia. There is evidence for an effect of diabetes-related processes on both neurodegenerative and vascular processes, thus contributing to both Alzheimer’s-like cognitive impairment, i.e., amnestic, and cerebrovascular-type cognitive impairment characterized by impairment in executive cognitive function.

This chapter reviews epidemiologic studies of the association between diabetes and cognitive impairment in large clinical or community-based studies, emphasizing studies in the United States. Type 1 diabetes is, in general, related to modest decrements in cognitive abilities, primarily in executive-frontal abilities. Type 2 diabetes seems to be more strongly related to vascular and non-amnestic forms of cognitive impairment, including non-amnestic mild cognitive impairment and vascular dementia, but it also seems to have a less strong association with amnestic forms of cognitive impairment, including amnestic mild cognitive impairment and Alzheimer’s dementia.

The relation of diabetes to cognitive impairment has therapeutic implications. There is conflicting evidence from clinical trials of diabetes interventions examining the effects of better glucose control on cognition and the brain. Lifestyle interventions among persons with diabetes and prediabetes do not seem to be related to better cognitive outcomes in the long term.

Despite many studies documenting the association between diabetes and cognitive impairment, the causal nature and the mechanisms of this association have not been fully established and require further study.

## Introduction

This chapter describes important concepts in cognitive impairment and epidemiologic data on cognitive impairment in the general U.S. population. Then, the relationship between diabetes and cognitive impairment is explored, including potential mechanisms and epidemiologic data linking the two conditions, as well as implications for treatment and prevention. The review of the epidemiologic data from diabetic cohorts emphasizes large longitudinal studies in the United States and Canada and clinical trials when available. Both type 1 diabetes and type 2 diabetes are covered in this chapter.

### Description of Cognitive Impairment

To study cognitive impairment, persons with and without diabetes are compared in performance of cognitive tests and by the presence or absence of cognitive dis orders, such as mild cognitive impairment (MCI) and dementia. A brief description of these types of cognitive impairment follows. Importantly, in this chapter, Alzheimer’s disease (AD) is referred to as one pathologic process underlying cognitive impairment, characterized by the presence of amyloid plaques and neurofibrillary tangles on brain autopsy, and not the manifestation of cognitive impairment, a frequent source of confusion. Dementia, the most severe clinical manifestation of AD, is referred to as AD dementia.

#### Performance in Cognitive Tests

The most frequently studied cognitive domains broadly defined are memory and executive-frontal abilities. Memory can be defined as the ability to recall an experience after it has ended (1). Memory is tested by repetition of words usually delivered verbally as lists of several words or as a part of tests of global cognition, such as the 5-minute recall of three items in the Mini Mental Status Exam (2). Memory problems are probably the most frequent cognitive complaints that bring patients to medical attention. Several key processes are involved in the long-term maintenance of memories. Consolidation, primarily located in the hippocampal formation, enables the acquisition of new memories (1). Consolidation is the first and most prominently affected process in AD dementia and its antecedent, amnestic MCI. Another key memory process is retrieval (1), which is most affected by lesions disturbing the frontal lobe-subcortical circuits in the brain. Retrieval deficits manifest as difficulty in recalling words or objects that can be aided by giving multiple choice options or cues (recognition).

Executive-frontal abilities include those skills that are used to plan and execute complex tasks and comprise different processes, such as attention, working memory, and impulse control. Executive-frontal abilities are most often affected by lesions that disrupt the frontal subcortical networks (3), the same network that supports memory retrieval. A common type of lesion that can affect frontal subcortical networks in diabetes is cerebrovascular disease. Commonly used tests of executive-frontal abilities include digits forward and backward (a test in which persons are asked to repeat a number series forward and backward), the attention items of the Mini Mental Status Exam (2), and the Digit Symbol Substitution Test (DSST) of the Wechsler Adult Intelligence Scale (4).

An important consideration about the evaluation of performance on cognitive tests as outcomes is the judgment of the clinical significance of differences found between groups, for example, between persons with diabetes and those without diabetes. Some studies will report that persons with diabetes perform less well in a test than persons without diabetes and provide a difference size or the score in performance in both groups. It can be concluded from such data that persons with diabetes will perform less well than persons without diabetes, but the clinical importance of such a difference is un certain. One way to overcome this problem is by providing standardized differences. One common metric used is Cohen’s d (5), which is calculated as the difference between the means divided by the pooled standard deviation. A Cohen’s d of 0.2 is considered small, 0.5 is considered medium, and 0.8 is considered large. Some sections of this chapter make reference to Cohen’s d in the interpretation of effect sizes.

#### Mild Cognitive Impairment

MCI is a diagnostic category used to capture the transitional state between normal cognitive function and dementia (6,7) and has become a target for interventions (8). The feature that differentiates MCI from dementia is functional impairment: individuals with MCI still have the ability to function in daily activities (7), while persons with dementia do not. In MCI, general cognitive performance is well preserved, but performance in one cognitive domain falls below expectations for age and education. Typically, it is defined following cutpoints of “pass/fail” results on neuropsychological tests (e.g., 1.5 standard deviations of established norms). This threshold is arbitrary, and the field of cognitive disorders has become interested in even milder forms of cognitive impairment (e.g., using a threshold of 1.0 standard deviations rather than 1.5), which some have termed pre-MCI (9).

MCI can be classified as amnestic and non-amnestic MCI. Amnestic MCI involves memory impairment, while non-amnestic MCI involves predominantly non-memory domains, such as frontal-executive abilities. Amnestic MCI is believed to be an early manifestation of AD and an antecedent of AD dementia, while non-amnestic MCI, such as executive MCI, may be a form of vascular cognitive impairment (VCI) (6). In VCI, cognitive impairment may present slowly and incrementally as subclinical cerebrovascular disease worsens (seen as white matter hyperintensities [WMH] on brain imaging, called mini-strokes by clinicians, and “silent infarcts”), or it may suddenly appear after an infarct. In general, VCI affects executive-frontal abilities and memory retrieval and, similar to amnestic MCI, may or may not progress to the syndrome of dementia. Some experts believe that the cognition field has paid more attention to cognitive impairment due to AD to the detriment of the identification of the other forms of cognitive impairment described here, particularly those related to executive abilities (10).

This relative lack of research is particularly relevant to persons with diabetes, who likely have cerebrovascular disease and, thus, are at high risk of cognitive impairment involving executive-frontal functions.

#### Dementia

Dementia is a syndrome characterized by impairment of memory and other cognitive abilities, as well as behavior disorder severe enough to impair the ability to live independently (11). Dementia is the most extreme form of cognitive impairment and the one most often identified in research and clinical practice due to its clinical significance. The most common cause of late-onset dementia is AD (12), comprising between 60% and 80% of cases. Vascular dementia is the second most common cause, comprising about 10% of cases, but approximately 50% of cases of dementia have a vascular component (12). Memory may be affected in vascular dementia, but the main cognitive domains affected are generally related to executive-frontal abilities. An important subgroup of dementia cases, the size of which likely differs across populations, has mixed pathology, having both neurodegenerative lesions typical of AD and cerebrovascular disease, which is “typical” of vascular dementia (13). This mixed dementia is particularly important when discussing cognitive impairment in diabetes, because diabetes is well known to be a risk factor for cerebrovascular disease (14), but whether it causes neurodegenerative disease is less clear (10). Other causes of dementia, such as frontotemporal dementia and Lewy body disease, are less common (15), are not known to be related to diabetes, and are thus not discussed in this chapter.

### Epidemiology and Burden of Cognitive Impairment in the General U.S. Population

#### Frequency

Major epidemiologic studies have shown that dementia prevalence increases logarithmically after age 70 years (16) and may reach 50% in persons age ≥85 years (17). According to the 2014 Alzheimer’s Disease facts and figures report from the Alzheimer’s Association (12), 11% of people age ≥65 years and one-third of people age ≥85 years have late-onset AD dementia. Given the longer life expectancy of the population, cases of AD dementia in persons age ≥65 years are expected to increase by 40% from current numbers by 2025 (12). Estimates from the 2010 Census revealed that in 2010, there were 4.7 million cases of AD dementia, of whom 0.7 million were age 65–74 years, 2.3 million were 75–84 years, and 1.8 million were ≥85 years (18). Based on these estimates, the projected number of AD dementia cases in 2050 will be 13.8 million, with 7.0 million age ≥85 years. AD dementia is the sixth leading cause of death in the United States and the fifth leading cause for those age ≥65 years (15). As previously mentioned, vascular dementia is the second most common cause, comprising about 10% of cases, but approximately 50% of all cases of dementia have a vascular component (12).

The prevalence of amnestic MCI varies from 3% to 20% depending on the criteria applied (19) and the population studied. Estimates increase from about 1% in persons age 60 years to 25% at age 85 years (20). The Aging, Demographics, and Memory Study estimated the prevalence of cognitive impairment without dementia, similar to MCI, in a representative sample of 856 persons in the United States (21). Twenty-two percent of persons age ≥71 years met the study criteria for cognitive impairment without dementia. Among those, 8% died and 12% progressed to dementia on an annual basis. Persons with amnestic MCI may progress to AD dementia at the rate of nearly 10%–15% per year (6) compared to 1%–2% in elderly persons with normal cognition (7).

It is important to put the epidemiology of cognitive impairment in the context of the epidemiology of diabetes in the United States. Over 100 million U.S. adults have diabetes or prediabetes: 25 million have diabetes and 79 million have prediabetes (22), comprising one-third of the U.S. population. This high prevalence is accounted for in large part by the age group most at risk for cognitive impairment, persons age ≥60 years in whom the prevalence of pre diabetes and diabetes is >50% (>60% in minorities) (22,23). A large proportion of this prevalence is accounted for by non-Hispanic blacks and Hispanics (22,24,25), who have about twice the prevalence of diabetes compared to non-Hispanic whites (22,24).

An interesting aspect of dementia is that it has ethnic differences similar to those found in type 2 diabetes. In a study from Northern Manhattan in New York City, Hispanics and non-Hispanic blacks had approximately double the prevalence of dementia compared to non-Hispanic whites (26,27). In the same cohort from Northern Manhattan, it was estimated that the higher prevalence of diabetes in minorities could account for some of the ethnic disparities in cognitive impairment, including MCI and dementia, among persons age ≥65 years (28).

#### Causes, Risk Factors, Prevention, and Treatment of Cognitive Impairment

The pathologic hallmark of AD is the presence of amyloid plaques and neurofibrillary tangles identified in brains that have come to autopsy (29). To date, the accumulation of amyloid and its prevention (30) have received the most attention in studies of causes, prevention, and treatment of AD.

In 2010, an expert panel from the National Institutes of Health concluded that there was insufficient evidence to recommend treatment or prevention for AD dementia (31). The genetic causes of early-onset, familial AD dementia are known (32), but this form represents a minority of cases and is not the focus of this chapter. APOE-ε4, encoding a form of apolipoprotein E, is the only robust genetic susceptibility risk factor for late-onset AD dementia, occurring in up to 50% of cases. However, it has not proved useful for diagnosis, prevention, or treatment (33,34,35). In addition, APOE-ε4 has lower predictive value in non-Hispanic blacks and Hispanics compared to non-Hispanic whites (27,33). Among nongenetic risk factors, older age, lower education, and diabetes (36) are the most robust. Studies of hypertension in relation to dementia have shown that mid-life exposure to risk factors may be a better indicator of future risk for dementia than measures obtained close to the time that cognitive impairment is detected (37,38). Other factors, such as smoking, dyslipidemia, diet, and physical activity, have been studied, but results are inconsistent (39). Risk factors for VCI (40) are mainly those associated with cerebrovascular disease, including diabetes and other vascular risk factors, such as hypertension and dyslipidemia (41).

## Potential Mechanisms Linking Diabetes and Cognitive Impairment

Diabetes and its related conditions, adiposity and hyperinsulinemia, and their clustering with other vascular risk factors, such as hypertension and dyslipidemia (42), are known to increase the risk for cerebrovascular disease (14,41,43,44,45,46). In addition, insulin or diabetes-related byproducts may affect the amyloid cascade that is thought to be responsible for AD (47). Thus, potential mechanisms linking diabetes with cognitive impairment are classified as cerebrovascular and non-cerebrovascular.

### Cerebrovascular Substrates

Infarcts, ascertained by clinical history as strokes causing neurologic deficits (48) or identified as focal lesions on brain imaging (49), are related to a higher risk of AD dementia and vascular dementia. The mechanisms for the association with AD dementia are not clear. However, the presence of infarcts in persons with AD neuropathology may result in an increase in brain injury and increase the likelihood of reaching a clinical dementia endpoint in the presence of such neuropathology (50,51).

FIGURE 24.1 Relation of Glycemia and Insulin Resistance to Risk of Alzheimer’s Disease Neuropathology, the Hisayama Study, 1998–2003

Odds ratios for each tertile of (A) glucose, (B) insulin, and (C) HOMA-IR versus the lowest tertile for the presence of neuritic plaques. Model 1: adjusted for age and sex. Model 2: adjusted for age, sex, systolic blood pressure, total cholesterol, body mass index, current smoking, regular exercise, and cerebrovascular disease. Conversions for glucose and insulin values are provided in Diabetes in America Appendix 1 Conversions. HOMA-IR, homeostasis model assessment of insulin resistance.

* p<0.05 versus the lowest tertile

† p<0.10 versus the lowest tertile

Bar graphs showing that increased glycemia and insulin resistance measured ten years before autopsy were related to increased risk of Alzheimer’s disease neuropathology.

SOURCE: Reference 87, copyright © 2010 Wolters Kluwer, reprinted with permission

White matter disease, called mini-strokes by clinicians, is ascertained as WMH, also known as leukoaraiosis, on brain imaging (40). WMH may represent microvascular disease in the brain or demyelination. However, the nature of WMH is still not well understood. WMH are thought to be ischemic in origin in the same way that infarcts are (52) and, thus, have been proposed as surrogate markers of cerebrovascular disease (52). However, WMH are common in AD dementia, and some may be related to cerebral amyloid angiopathy (53,54,55,56), a correlate of AD, inflammation, or other demyelinating processes. WMH are common correlates of cognitive impairment in diabetes (57), but it is unclear whether these WMH are markers of microvascular injury or if they represent a process related to amyloid deposition or another neurodegenerative process.

### Non-Cerebrovascular Mechanisms

Hyperinsulinemia caused by insulin resistance is an important antecedent and companion of type 2 diabetes (58,59). Hyperinsulinemia is a plausible risk factor for AD dementia, independent of cerebrovascular disease for several reasons. Insulin can cross the blood brain barrier (60), and peripheral insulin infusions in the elderly may affect amyloid levels in cerebrospinal fluid (61), an indirect marker of AD risk. In addition, insulin receptors in important brain structures, including the hippocampus and entorhinal cortex, are affected early in AD (62). Insulin and amyloid are competing substrates for insulin-degrading enzyme, which has been linked to clearance of amyloid in the brain (63). Insulin in the brain can increase the deposition of amyloid and Tau protein phosphorylation, which are central to the pathogenesis of AD (60). The pathways relating insulin in the periphery with amyloid clearance in the brain are multiple and complex (64). One potential pathway is that peripheral hyperinsulinemia downregulates insulin uptake in the blood brain barrier due to saturation over physiologic levels (65). This may result in reduction of insulin levels in the brain, as well as downregulation of the expression of insulin-degrading enzyme (66) and reduction in its related amyloid clearance function (63). This complex observation has been used to support the seemingly paradoxical use of rosiglitazone, an insulin sensitizer (67,68), and intranasal insulin (69) in the treatment of AD dementia.

Advanced glycation endproducts (AGEs) are closely linked with glycemia and diabetes and have also been related to AD. Glycated hemoglobin (A1c), used by clinicians to track diabetes control, is the most common example of an AGE. With hyperglycemia, diabetic animal and human tissues increase both AGEs and their receptors (RAGE) (70,71,72), and AGEs are known to be related to the traditional microvascular complications of type 2 diabetes (73,74,75,76,77,78). Increased expression of RAGE is also observed in AD dementia (79,80,81), and expression of RAGE is enhanced in blood vessels near amyloid deposits in AD brains (79,82).

Several studies have examined the relation between diabetes and dementia mechanisms, particularly surrogate markers of AD, and found conflicting results. These markers have included neuropathology studies, brain imaging studies, and studies of other biomarkers. Neuropathology studies from 233 participants in the Religious Orders Study, a study of deceased older Catholic nuns, priests, and brothers from across the United States (83), and from a study of 385 nursing home residents who underwent autopsy (84) found that a history of diabetes was not related to AD neuropathology, similar to a study in a Finnish population (85). However, a study of Japanese Americans in Hawaii found that diabetes was associated with higher prevalence of AD neuropathology (86). The most compelling neuropathology study to date found, in a Japanese sample, that increased glycemia and insulin resistance measured 10 years before autopsy were related to increased risk of AD neuropathology (Figure 24.1) (87). One brain imaging study in the United States found that insulin resistance was related to a profile of brain metabolism on brain positron emission tomography (PET) that is consistent with AD (88). Similarly, another brain imaging study from the United States among 749 persons with a mean age of 79 years found that diabetes was associated with a brain metabolism pattern similar to AD, but not with increased amyloid brain accumulation, as ascertained with brain PET with an amyloid ligand (Figure 24.2) (89). A study from the Baltimore Longitudinal Study of Aging (BLSA) (90) found among 197 persons with autopsy at a mean age of 88 years that hyperglycemia, insulin resistance, and diabetes assessed approximately at age 66 years were not associated with increased brain AD pathology. The same study had data on 53 subjects with brain amyloid PET acquired at a mean age of 79 years and also found no evidence of a relation with brain amyloid.

The conflicting results of these studies do not help resolve the question of whether diabetes is related to brain amyloid accumulation. The limitations of the neuropathology studies include survival bias and selection bias and the lack of proper ascertainment of diabetes status compared with the previously mentioned Japanese study with detailed data on glycemia and insulin resistance that found that hyperglycemia and insulin resistance were related to AD pathology (87). The limitations of the few amyloid brain imaging studies include old age and small clinic samples, which also suffer from survival and selection biases (i.e., persons with diabetes may have a higher mortality risk that could result in survival bias and affect the study of dementia and neuropathology outcomes).

FIGURE 24.2 Patterns of Brain Metabolism and Amyloid Brain Accumulation by Positron Emission Tomography, by Diabetes Status and Cognitive Impairment, Mayo Clinic Study of Aging, 2006–2012

Box plots for 18F-FDG and 11C-PiB retention ratio in Alzheimer’s disease signature regions by diabetes mellitus (DM) in cognitively normal subjects and those with mild cognitive impairment (MCI). ● = women; ○ = men.

Box plots showing that diabetes was associated with a brain metabolism pattern similar to Alzheimer’s disease, but not with increased amyloid brain accumula-tion.

SOURCE: Reference 89, copyright © 2014 Society of Nuclear Medicine and Molecular Imaging, reprinted with permission

## Type 1 Diabetes and Cognitive Impairment

Historically, most research on the relationship between type 1 diabetes and cognitive impairment was conducted on relatively small “convenience” samples, and was restricted to children or young and middle-aged adults. Cognitive status was typically measured with a battery of neuropsychological tests that assessed multiple cognitive domains, including attention/concentration, learning and memory, mental and motor speed, visual perceptual skills, and reasoning or “executive function” (91,92). Because the focus was on identifying mild to moderate decrements in cognitive functioning, dysfunction was operationally defined in terms of performance differences between demographically similar subjects with and without diabetes. Most recent studies have expressed these as standardized differences (e.g., z score differences; Cohen’s d) (93). With very few exceptions (94,95), researchers have not made formal ratings of clinically significant impairment like dementia or MCI, largely because it is quite unusual to find clinical evidence of serious cognitive impairments in this patient population. Drawing on results from 15 studies comprising 1,029 subjects with diabetes and 751 control subjects, Gaudieri et al. (96) found modestly poorer performance among those children and adolescents with diabetes. Effects were largest for measures of “crystalized intelligence”—factual information about the world, verbal learning, and visual and motor integration. Because a number of studies have consistently indicated that children with an “early onset” of diabetes—usually diagnosis before age 6 or 7 years—perform more poorly than those with a later onset of diabetes (97), the meta-analysis was repeated, but comparing early-onset with later-onset subjects. The magnitude of the cognitive differences was found to be somewhat larger in persons with early onset of diabetes compared with later onset, with more domains equal to or greater than an effect size (Cohen’s d) of 0.15, considered a small difference as compared with controls. Taken together, these results support the view that in children and adolescents, diabetes is associated with modest decrements on a range of cognitive skills, with these effects being greatest in those youngsters who were diagnosed with diabetes early in life. Another meta-analysis, adding several newer studies (24 studies published between 1980 and 2005), identified a generally similar pattern of results (98), with modest differences between diabetic and nondiabetic samples (Cohen’s d 0.15–0.30) evident on tests of verbal and performance intelligence, as well as on measures of visuospatial ability, motor speed, attention, and reading and writing.

In terms of cognition in adults with type 1 diabetes, Brands et al. (99) published a meta-analysis of 33 studies published between 1980 and 2004 that included adults age >18 years and a comparison group of subjects without diabetes. In virtually all studies, subjects were age <50 years at the time of the cognitive assessment. As illustrated in Figure 24.3 (99), adults with type 1 diabetes performed consistently more poorly than controls on measures of overall cognition, intelligence, psychomotor efficiency, speed of information processing, cognitive flexibility, attention, and visual perceptual skills. The largest effect sizes (Cohen’s d 0.5–0.7) were found on measures of crystalized intelligence, fluid intelligence (e.g., problem-solving, reasoning), psychomotor efficiency, and cognitive flexibility, which fall under the umbrella of non-amnestic cognitive function. It is noteworthy that with the exception of measures of crystalized intelligence, the other cognitive domains that were most affected by diabetes tended to be those that required rapid responding or were otherwise time-limited. Despite the relatively small sample sizes of the studies included in this analysis, as well as the wide range of measures used by the different researchers, these results are remarkably consistent with those reported in studies of children and adolescents: intelligence, as measured by formal IQ tests, is consistently lower—by about 3 to 5 points on average (the majority of the general population is between 85 and 115 points of IQ)—and performance is slower—by 5%–15%—on tasks that require attention and rapid responding.

FIGURE 24.3 Meta-Analysis of Cognitive Performance Among Adults With Type 1 Diabetes

Standardized effect sizes (Cohen’s d) and 95% confidence intervals for the cognitive domains in patients with type 1 diabetes compared with nondiabetic control subjects. Number of patients included in each domain is listed between parentheses. Nonsignificant p-values are not shown. Points to the left of 0 indicate worse cognitive performance in persons with type 1 diabetes compared to controls without diabetes.

Forest plot showing that adults with type 1 diabetes preformed consistently more poorly than controls on measure of overall cognition and other cognitive performance measures.

SOURCE: Reference 99, copyright © 2005 American Diabetes Association, reprinted with permission from The American Diabetes Association. References for individual studies are available from Reference 99.

The only large-scale study to comprehensively assess adolescents and adults with type 1 diabetes over time is the Diabetes Control and Complications Trial (DCCT), conducted in 29 sites in the United States and Canada (100). This clinical trial, which compared the effects of intensive insulin therapy (multiple daily injections) with conventional therapy (one or two daily injections), was designed to test the hypothesis that intensive therapy delayed or prevented the development of microvascular and neuropathic complications. Because intensive therapy was known to increase the incidence of severe hypoglycemia and because earlier studies had demonstrated that severe hypoglycemia could adversely affect the structural and functional integrity of the brain, the DCCT study group developed a comprehensive battery of neurocognitive tests that was administered at study entry and repeated at years 2, 5, 7, and/or study end. Data from 1,441 subjects, followed for an average of 6.5 years, demonstrated that intensive insulin therapy did not differentially disrupt functioning on any of the eight cognitive domains studied. Despite high rates of hypoglycemia in the study group, there was no relationship between moderately severe hypoglycemia and performance on any cognitive test (95,101). Use of an innovative clinical rating procedure (102) showed very low rates of clinically significant worsening over time (by year 5, only 23 of 1,383 subjects showed significant cognitive decline), and these effects were unrelated to hypoglycemia.

The Epidemiology of Diabetes Interventions and Complications (EDIC) study, a follow-up assessment of the DCCT cohort (N=1,144), studied a mean of 18 years following study entry, also showed no between-group differences on any cognitive domain nor any relationship between recurrent episodes of hypo glycemia and change in cognitive functioning over time (Figure 24.4) (103). However, poorer metabolic control, operationalized as a time-weighted A1c value of ≥8.2% (≥66 mmol/mol), was associated with consistently poorer performance over time on two cognitive domains: psychomotor efficiency and motor speed.

Subsequent analyses, focusing on predictors of cognitive changes over time, demonstrated that after controlling for age and education, proliferative retinopathy, renal complications, and time-weighted A1c values were each independently and significantly associated with declining performance on measures of psychomotor efficiency (104). This work is consistent with earlier longitudinal studies (105) that link the development of microvascular complications to psychomotor slowing in adults with type 1 diabetes.

FIGURE 24.4 Effects of DCCT Treatment Group, Severe Hypoglycemia, and Glycated Hemoglobin on Changes in Cognition, From Entry Into DCCT to Year 12 in the EDIC Study

The bars show the changes within cognitive domains between cognitive testing at baseline in DCCT and follow-up testing (a mean of 18 years after baseline) expressed as (A) changes in z scores for intensive versus conventional treatment, (B) frequency of episodes of severe hypoglycemia (coma or seizure), and (C) mean glycated hemoglobin values. Across the three groups, higher levels of glycated hemoglobin were associated with moderate declines in psychomotor efficiency (p<0.001) and motor speed (p=0.001), but no other cognitive domain was affected significantly. Cognitive domains are numbered as follows: 1, problem solving; 2, learning; 3, immediate memory; 4, delayed recall; 5, spatial information; 6, attention; 7, psychomotor efficiency; and 8, motor speed. Conversions for glycated hemoglobin values are provided in Diabetes in America Appendix 1 Conversions. DCCT, Diabetes Control and Complications Trial; EDIC, Epidemiology of Diabetes Interventions and Complications study.

Bar graphs showing no changes within cognitive domains between baseline and 12 years follow up by intensive vs. conventional diabetes treatment or by number of hypoglycemic events.

SOURCE: Reference 103, copyright © 2007 Massachusetts Medical Society, reprinted with permission

## Type 2 Diabetes and Cognitive Impairment

### Diabetes, Cognitive Decline, and Mild Cognitive Impairment

The difference in cognitive function between those with and without diabetes is relatively robust across cohort studies, although results vary in terms of which specific functions differ between the two groups. Over 4 years, a cohort of 999 individuals age 44–89 years was followed in the Rancho Bernardo Study, a population-based study conducted in suburban southern California. Diabetes, ascertained by glucose tolerance testing, was associated with faster decline in a verbal fluency test (a test of executive-frontal abilities), but not a decline in the Mini Mental Status Exam (a test of global cognition) or Trail Making Tests (another test of executive-frontal abilities) (106). The Atherosclerosis Risk in Communities Study (ARIC) was a prospective epidemiologic study of 10,963 persons age 47–70 years in four U.S. communities (Washington County, Maryland; Forsyth County, North Carolina; Jackson, Mississippi; and Minneapolis, Minnesota). ARIC showed that diabetes, ascertained by self-report or fasting glucose, was a strong predictor of decline in the DSST of the Wechsler Adult Intelligence scale and the word fluency test, both tests of executive-frontal abilities, after 6 years of follow-up (107).

Self-reported diabetes was related to a twofold higher risk of developing MCI among 7,027 osteoporotic postmenopausal women with a mean age of 66 years participating in a clinical trial of the osteoporosis medication raloxifene in 25 countries, including the United States (108). A multiethnic study of 1,088 subjects age ≥65 years in New York City found that diabetes was related to a higher risk of cognitive impairment-without dementia with stroke, but not of cognitive impairment-without dementia without stroke, after adjusting for demographic variables and the presence of the APOE-ε4 allele (26). A Canadian prospective study in 5,574 persons age ≥65 years similarly found that diabetes was related only to VCI-without dementia (109). Another study in 918 subjects age ≥65 years in New York City found that diabetes was related to a higher risk of both amnestic and non-amnestic MCI, highlighting the importance of diabetes for both AD and VCI (110). A study of 1,640 subjects age 70–80 years from Olmstead County, Minnesota, reported that longer diabetes duration and treatment with insulin, a surrogate marker of diabetes severity, were related to higher MCI risk (111).

### Diabetes and Dementia

Numerous studies conducted in a wide range of ethnic groups have examined the relation between diabetes and dementia (112,113). Table 24.1 shows the results of representative prospective studies in the United States. In general, the association between diabetes and dementia seems to be strongest for vascular dementia or AD dementia with vascular comorbidity, paralleling the findings for studies examining cognitive performance and non-dementia cognitive impairment as outcomes. One of the most compelling reports documenting the association between diabetes and dementia came from a study of 2,067 subjects age ≥65 years from Washington State with repeated measures of glycemia (114). In this study, increased glucose levels were related to a higher risk of dementia both among persons with and without diabetes. For example, for an average glucose level of 190 mg/dL (10.55 mmol/L) compared with 160 mg/dL (8.88 mmol/L), there was a 40% increased risk of dementia (Figure 24.5) (114). Some studies have also reported a greater risk of dementia among persons with diabetes and the APOE-ε4 allele compared to persons with one of these risk factors or others (86,115), suggestive of gene-environment interaction.

TABLE 24.1 Summary of Epidemiologic Studies From North America Relating Type 2 Diabetes and Dementia

YEARS (REF.) | POPULATION | SAMPLE | STUDY CHARACTERISTICS | STATISTICS
1970–1984 (153) | Historical cohort in Rochester, Minnesota | 1,455 persons with diabetes; age ≥45 years | Dementia ascertained by medical record abstraction. Standardized morbidity ratios calculated using expected age- and sex-specific dementia rates. | Persons with diabetes exhibited significantly increased risk of all dementia (RR 1.66, 95% CI 1.34–2.05) and Alzheimer’s disease (AD) dementia (for men, RR 2.27, 95% CI 1.55–3.31; for women, RR 1.37, 95% CI 0.94–2.01).
1991–1996 (26) | Multiethnic cohort from New York City recruited between 1992 and 1994 | 1,262 subjects without dementia at baseline; mean age 75.6 years | Diabetes diagnosed by self-report or use of diabetes medications. Dementia and dementia subtype diagnosed by standard research criteria. | The adjusted relative risk of AD dementia among persons with diabetes compared to those without diabetes was 1.3 (95% CI 0.8–1.9). The adjusted relative risk of stroke-associated dementia in persons with diabetes was 3.4 (95% CI 1.7–6.9).
1991–1992 (109) | Canadian Study of Health and Aging | 5,574 subjects; mean age 74±6.4 years | Diabetes diagnosed by self-report. Dementia diagnosed by research criteria. | Diabetes at baseline was associated with incident vascular dementia (RR 2.03, 95% CI 1.15–3.57), but not with mixed AD/vascular dementia (RR 0.87, 95% CI 0.34–2.21), or AD dementia (RR 1.30, 95% CI 0.83–2.03), or all dementias (RR 1.26, 95% CI 0.90–1.76).
1991 and 1994 (86) | Population-based cohort of Japanese American men enrolled in the Honolulu-Asia Aging Study | 2,574 subjects; mean age 76.9 years | Diabetes ascertained by interview and direct glucose testing. Dementia assessed by research criteria. | Diabetes was associated with total dementia (RR 1.5, 95% CI 1.01–2.2), AD dementia (RR 1.8, 95% CI 1.1–2.9), and vascular dementia (RR 2.3, 95% CI 1.1–5.0). Individuals with both type 2 diabetes and the APOE-ε4 allele had a relative risk of 5.5 (95% CI 2.2–13.7) for AD dementia compared with those with neither risk factor.
1994–2003 (154) | Religious Orders Study across the United States | 824 nuns, priests, and brothers; mean age 75 years | Diabetes ascertained by self-report or use of medications. AD ascertained by research criteria. | Diabetes was related to higher risk of AD dementia (HR 1.65, 95% CI 1.10–2.47).
1964–1973 and 1994–2003 (155) | Participants of a health maintenance organization in Northern California | 8,845 subjects | Diabetes ascertained when participants were between ages 40 and 44 years. Dementia ascertained when participants were between ages 70 and 74 years. Both diabetes and dementia ascertained from medical records. | Diabetes was related to a higher risk of dementia (HR 1.46, 95% CI 1.19–1.79).
1992–2000 (115) | Cardiovascular Health Study | 2,547 subjects; mean age 74.67 years | Diabetes ascertained by fasting blood glucose or clinical history. AD ascertained by research criteria. | Diabetes was only related to dementia (HR 1.44, 95% CI 1.03–2.01), AD dementia (HR 1.62, 95% CI 0.98–2.67), and mixed AD (HR 1.75, 95% CI 1.00–3.04), but not vascular dementia (HR 0.80, 95% CI 0.30–2.09). Compared with those who had neither diabetes nor APOE-ε4, those with both factors had a significantly higher risk of AD dementia (HR 4.58, 95% CI 2.18–9.65) and mixed AD (HR 3.89, 95% CI 1.46–10.40).
1999–2007 (156) | Cohort from New York City recruited between 1999 and 2001 | 1,488 subjects; mean age 76.0 years | Diabetes ascertained by self-report. Dementia ascertained by research criteria. | Diabetes associated with a higher risk of AD dementia (HR 1.6, 95% CI 1.0–2.6) and vascular dementia (HR 5.4, 95% CI 0.3–95.0).
1994–2004 (114) | Cohort from the Group Health Cooperative in Washington State | 2,067 subjects; mean age 76 years | Glycemia measured with glucose or glycated hemoglobin (A1c). | Among participants without diabetes, higher average glucose levels within 5 years before baseline were related to an increased risk of dementia (p=0.01). For a glucose level of 115 mg/dL compared with 100 mg/dL, the adjusted hazard ratio for dementia was 1.18 (95% CI 1.04–1.33). Among participants with diabetes, higher average glucose levels were also related to an increased risk of dementia (p=0.002); for a glucose level of 190 mg/dL compared with 160 mg/dL, the adjusted hazard ratio was 1.40 (95% CI 1.12–1.76).

Conversions for glucose values are provided in Diabetes in America Appendix 1 Conversions. AD, Alzheimer’s disease; CI, confidence interval; HR, hazard ratio; RR, relative risk.

SOURCE: References are listed within the table.

FIGURE 24.5 Risk of Incident Dementia Associated With the Average Glucose Level During the Preceding 5 Years, According to the Presence or Absence of Diabetes, Adult Changes in Thought Study, 1994–2004

Solid curves represent estimates of the hazard ratios for the risk of incident dementia across average glucose levels relative to a reference level of 100 mg/dL for participants without diabetes (Panel A) and 160 mg/dL for participants with diabetes (Panel B). The dashed lines represent pointwise 95% confidence intervals. Conversions for glucose values are provided in Diabetes in America Appendix 1 Conversions.

Line graphs showing that increased glucose levels were related to a higher risk of dementia both among persons with and without diabetes.

SOURCE: Reference 114, copyright © 2013 Massachusetts Medical Society, reprinted with permission

#### Caveats in the Epidemiologic Study of Diabetes and Dementia

The study of diabetes and dementia in older age is affected by competing risks of morbidity and mortality, which may limit the participation of persons with diabetes at baseline or follow-up studies. In other words, since diabetes is an important cause of morbidity and mortality, persons with diabetes may not live long enough or be healthy enough to participate in prospective studies examining the association between diabetes and cognitive impairment, which usually involve populations age ≥65 years. This issue is illustrated by a new analysis of the National Nursing Home Survey 2004 conducted for Diabetes in America, 3rd edition. This analysis, based on International Classification of Diseases, Ninth Revision (ICD-9), medical record coding of dementia, showed the prevalence of dementia was lower in persons with diabetes (13.8%) compared to persons without diabetes (21.7%) (Table 24.2). This difference was consistent in all age groups, both sexes, and across race/ethnicity groups (Table 24.2) and among dementia cases residing inside or outside of a dementia care unit (data not shown). This type of bias could also explain the conflicting results of studies examining the association of diabetes and markers of AD pathology on autopsy and brain imaging mentioned previously.

TABLE 24.2 Prevalence of Dementia in Nursing Home Residents, by Diabetes Status, Age, Sex, and Race/Ethnicity, U.S., 2004

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Diabetes | No Diabetes
Overall | 13.8 (0.73) | 21.7 (0.62)
Age (years)
<20 | ^2^ | ^2^
20–44 | ^2^ | ^2^
45–54 | ^2^ | 5.2 (1.56)
55–64 | 3.6 (1.21)^1^ | 10.2 (1.61)
65–74 | 9.3 (1.46) | 16.0 (1.40)
75–84 | 15.0 (1.29) | 25.7 (1.03)
85–94 | 19.5 (1.55) | 24.8 (0.90)
≥95 | 14.4 (3.89) | 19.3 (1.55)
Sex
Male | 11.8 (1.17) | 17.4 (1.00)
Female | 14.7 (0.88) | 23.4 (0.69)
Race/ethnicity
Non-Hispanic white | 15.1 (0.89) | 22.6 (0.68)
Non-Hispanic black | 10.5 (1.50) | 17.6 (1.49)
Hispanic | 7.5 (2.23) | 18.0 (2.90)

Diabetes is based on ICD-9 codes 250, 357.2, 362.0, 366.41, 648.0, and 775.1. Dementia is based on ICD-9 codes 290, 294.1, 294.2, and 331. ICD-9, International Classification of Diseases, Ninth Revision.

1 Relative standard error >30%–40%

2 Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Nursing Home Survey 2004

## Therapeutic and Prevention Implications

The association between diabetes and cognitive impairment has three main practical implications: first, diabetes treatment may alter the trajectory to cognitive impairment; second, interventions that prevent diabetes could prevent cognitive impairment; and third, specific diabetes medications could be used in the treatment and prevention of cognitive impairment.

### Diabetes Treatment and Cognitive Impairment

The Action to Control Cardiovascular Risk in Diabetes-Memory in Diabetes (ACCORD-MIND) study (n=2,790) was designed to examine the difference between therapeutic strategies in the rate of cognitive decline and related structural brain changes (116). MIND was embedded in the 2 by 2 factorial ACCORD therapeutic strategy trial that randomized 10,251 persons with longstanding type 2 diabetes, age 55–80 years, and who were at high risk for cardiovascular events in 77 sites in the United States and Canada. All participants were randomized to receive either the intensive glycemic control strategy (target A1c <6.0% [<42 mmol/mol]) or a standard glycemic control strategy (A1c 7.0%–7.9% [53–63 mmol/mol]), with the hypothesis that the more intensive therapeutic strategy would reduce the rate of cardiovascular events more than the standard strategy. The trial also had embedded in it a lipid trial (n=5,518), which tested whether within the context of good glycemic and lipid control (target low-density lipoprotein [LDL] cholesterol level <100 mg/dL [<2.59 mmol/L]) participants receiving a fibrate had fewer cardiovascular events than those receiving placebo. Also embedded was a blood pressure trial that compared cardiovascular events between a therapeutic strategy that followed standard guidelines (systolic blood pressure <140 mmHg) and one that aimed to lower systolic blood pressure goals (<120 mmHg).

The primary outcomes analysis of the MIND substudy focused on the glycemia trial and whether the intensive therapeutic strategy compared to the standard strategy reduced the risk of cognitive decline, measured with three tests covering memory and executive function, in the subset of MIND participants (mean age 62.5 years) (116). This analysis also assessed total brain volume, the primary brain structure outcome, on a subset of MIND participants who underwent brain magnetic resonance imaging. No differences were found between the treatment groups for the cognitive outcomes, but participants in the intensive treatment arm showed larger (better) total brain volumes (TBV). At 40 months, the TBV declined in all participants, but the decline was 0.41% per year in the intensive treatment arm compared with 0.57% per year in the standard treatment arm (Table 24.3) (116). Similarly, there were no differences in the cognitive outcomes in the blood pressure or lipid trials. However, one of the earlier analyses explored the relationship between the degree of hyperglycemia and cognitive status through a cross-sectional examination of baseline glycemic control and the cognitive scores obtained on the cognitive tests at baseline. It was reported that higher A1c levels were, indeed, associated with lower cognitive function in these patients (117). Another set of analyses found that depression in the MIND patients was associated with accelerated cognitive decline irrespective of which cognitive domains, treatment arms, or patient subgroups were assessed (118).

TABLE 24.3 Cognitive and MRI Primary and Secondary Outcomes, by Glycemia Arm, ACCORD-MIND Study

ENDPOINT | TIME POINT | LEAST SQUARES MEAN (95% CONFIDENCE INTERVAL) | | DIFFERENCE IN MEANS^†^
ENDPOINT | TIME POINT | Glycemia Intervention | | DIFFERENCE IN MEANS^†^
ENDPOINT | TIME POINT | Intensive^*^ | Standard^*^ | DIFFERENCE IN MEANS^†^
DSST | Baseline^‡^ | 52.55 | 52.55
DSST | 20 months | 51.51 (51.09–51.93) | 50.98 (50.57–51.39) | 0.53 (−0.06–1.12), p=0.0756
DSST | 40 months | 50.93 (50.50–51.35) | 50.61 (50.19–51.03) | 0.32 (−0.28–0.91), p=0.2997^§^
DSST | 40-month change | −1.62 (−2.05–−1.20) | −1.94 (−2.36–−1.52)
RAVLT | Baseline^‡^ | 7.51 | 7.51
RAVLT | 20 months | 7.87 (7.77–7.96) | 7.85 (7.76–7.94) | 0.02 (−0.11–0.15), p=0.7897
RAVLT | 40 months | 7.98 (7.88–8.08) | 7.99 (7.90–8.08) | −0.01 (−0.14–0.12), p=0.8929
RAVLT | 40-month change | 0.47 (0.37–0.57) | 0.48 (0.39–0.57)
Stroop | Baseline^‡^ | 32.0 | 32.0
Stroop | 20 months | 30.87 (30.16–31.57) | 31.46 (30.77–32.16) | −0.60 (−1.59–0.40), p=0.2375
Stroop | 40 months | 31.45 (30.73–32.17) | 32.06 (31.34–32.77) | −0.61 (−1.62–0.40), p=0.2383
Stroop | 40-month change | −0.55 (−1.27–0.17) | 0.06 (−0.66–0.77)
MMSE | Baseline^‡^ | 27.39 | 27.39
MMSE | 20 months | 27.26 (27.14–27.38) | 27.27 (27.15–27.39) | −0.01 (−0.18–0.16), p=0.9268
MMSE | 40 months | 27.05 (26.93–27.17) | 27.06 (26.93–27.18) | −0.01 (−0.18–0.16), p=0.9328
MMSE | 40-month change | −0.34 (−0.46–−0.22) | −0.33 (−0.46–−0.21)
MRI-TBV | Baseline^‡^ | 927.5 | 927.5
MRI-TBV | 40 months | 914.4 (912.5–916.4) | 909.8 (908.0–911.6) | 4.6 (2.0–7.3), p<0.0007^§^
MRI-TBV | 40-month change | −13.0 (−15.0–−11.1) | −17.7 (−19.5–−15.9)

ACCORD-MIND, Action to Control Cardiovascular Risk in Diabetes-Memory in Diabetes Study; DSST, Digit Symbol Substitution Test; MMSE, Mini Mental Status Exam; MRI-TBV, magnetic resonance imaging-total brain volume; RAVLT, Rey Auditory Verbal Learning Test.

* For DSST, RAVLT, and MMSE, a negative change value represents a decline in cognitive score. For the Stroop test, a positive change value represents a worsening score. For TBV, a negative change value represents a decline in volume.

† Difference calculated as intensive minus standard arm means.

‡ Baseline mean is the overall mean for both groups combined as measured prerandomization. This value is used to obtain the least squares means estimates at follow-up. Models are adjusted for baseline cognitive score and the factors used to stratify randomization: second trial assignment (BP or Lipid); randomized group allocation within the blood pressure (BP) and lipid trials, respectively; clinical center network; and history of cardiovascular disease.

§ Test of prespecified co-primary outcome.

SOURCE: Reference 116, copyright © 2011 Elsevier, reprinted with permission

The Informatics in Diabetes Education and Telemedicine Study (IDEATel) was a randomized trial of telemedicine versus usual care in 2,169 elderly persons with diabetes conducted in two sites in New York, a rural upstate site and an urban downstate site (119). The telemedicine intervention comprised a telemedicine unit with videoconferencing, email, and clinical data entry capabilities for patients who interacted with nurse care managers to improve their diabetes control. Persons in the IDEATel intervention group showed better diabetes control parameters compared to usual care (120). Estimated differences between the groups at year 5 were 0.29% for A1c, 3.84 mg/dL for LDL, and 4.32 mmHg for systolic blood pressure, all statistically significant and favoring the telemedicine intervention. Persons in the telemedicine intervention had less global cognitive decline during a maximum of 5 years of follow-up (Figure 24.6) (121). Importantly, the glycemic control goals of IDEATel followed glycemic guidelines (target A1c <7.0%) that were less stringent than the goals in ACCORD (A1c <6.0%), which showed increased mortality in its intensive glycemic control arm (122). Although the outcome of this study was global cognitive decline, memory was the strongest correlate of global cognitive function in a subset of patients with detailed neuropsychological testing. A mediation analysis demonstrated that among diabetes control parameters, lower glycemia measured with A1c, but not systolic blood pressure or LDL, was the main mediator for the association between improved control and cognitive performance (Figure 24.7) (121). Other analyses from this study restricted to the urban cohort in New York City found that mild memory or executive cognitive impairment (defined as cognitive performance worse than 1.0 standard deviations for the norms for age, sex, and education) were not associated with longitudinal diabetes control (123). Depression was also not associated with diabetes control, whether accompanied or not by mild executive or memory impairment (123). However, these studies did not measure whether persons with cognitive impairment received more assistance for their diabetes care, which could have underestimated the detrimental effects of cognitive impairment on diabetes control.

FIGURE 24.6 Effect of a Telemedicine Intervention Versus Usual Care on Global Cognitive Decline, Informatics for Diabetes Education and Telemedicine Study, 2000–2007

Comparison of changes in adjusted means in the Comprehensive Assessment and Referral Evaluation (CARE) Diagnostic Scale between the intervention and control from mixed models (adjusted for clustering) during a maximum follow-up of 5 years.

Line graph showing that adults with diabetes in a telemedicine intervention had less global cognitive decline during a maximum of 5 years of follow up compared to those with usual care.

SOURCE: Reference 121, copyright © 2011 Springer, reprinted with permission

The Action for Health in Diabetes (Look AHEAD) clinical trial, conducted in 21 sites in the United States, found that a lifestyle intervention among 978 persons with diabetes was not related to cognitive performance 8.1 years after trial enrollment (124), despite clinically significant weight loss in the intervention arm (125).

FIGURE 24.7 Path Diagram Depicting the Direct and Indirect Effects of the Telemedicine Intervention Through Hemoglobin A1c on Cognition, Informatics for Diabetes Education and Telemedicine Study

SAS PROC Mixed with a compound symmetry covariance structure was used in the cognition analyses with an adjustment for clustering within primary care provider clusters. HgA1c was treated as a time-varying covariate in the cognition analyses. SAS PROC Mixed was used to predict HgA1c and included adjustments for clustering and heterogeneity of variances in group and residual variances and exponential terms to model the nonlinear distribution of HgA1c over time. A first order auto-regressive covariance structure was used for the HgA1c analyses. Up to six waves of data (baseline plus five follow-up) were included in the analyses. n=2,169. HgA1c, glycated hemoglobin.

Path diagram depicting the significant and direct effect of telemedicine on cognition and A 1 c as a mediator between telemedicine and cognition.

SOURCE: Reference 121, copyright © 2011 Springer, reprinted with permission

### Hypoglycemia and Cognitive Impairment

One of the main complications of diabetes treatment is hypoglycemia, which has long been hypothesized to be a potential mechanism explaining the presence of cognitive impairment in diabetes. A large longitudinal epidemiologic study in 16,667 enrollees in a managed care health plan in Northern California showed that persons with diabetes with reported hypoglycemic events were more likely to develop dementia (Table 24.4) (126). Persons with one episode of hypoglycemia had approximately a 26% increased risk of dementia, while persons with three or more episodes had nearly a doubling in risk of dementia. However, this study did not have information on cognitive performance at the time of hypoglycemia. Thus, the investigators could not rule out that persons who had the type of cognitive impairment that precedes dementia (i.e., MCI) were taking their diabetes medications inappropriately, making them more prone to hypoglycemia. Analysis of the ACCORD-MIND data showed that persons with poor performance at baseline in the DSST, a test of frontal-executive abilities, were more likely to have a hypoglycemic event (127). A 5-point poorer baseline score in the DSST (mean score 52.55) had a 13% increased risk of a first episode of hypoglycemia during a mean follow-up of 3.25 years. These results suggest that cognitive impairment could lead to hypoglycemia, presumably because of inappropriate compliance with diabetes treatment that leads to hypoglycemia, and not the other way around. The lack of an effect of hypoglycemia on cognition is supported by an analysis of the DCCT and its follow-up EDIC study in persons with type 1 diabetes, who are at high risk of hypoglycemic episodes due to insulin treatment and autonomic dysfunction (103). Severe hypoglycemia, which occurred in 40% of this cohort, was not related to cognitive decline during 18 years of follow-up, albeit in relatively young participants.

TABLE 24.4 Hypoglycemia and Risk of Incident Dementia

NUMBER OF HYPOGLYCEMIC EPISODES^†^ | NUMBER OF DEMENTIA CASES | HAZARD RATIO (95% CONFIDENCE INTERVAL)^*^
NUMBER OF HYPOGLYCEMIC EPISODES^†^ | NUMBER OF DEMENTIA CASES | Adjusted for Age (as Time Scale), BMI, Race/Ethnicity, Education, Sex, and Duration of Diabetes | Additionally Adjusted for Comorbidities^‡^ | Additionally Adjusted for 7-Year Mean A1c Level, Diabetes Treatment, and Years of Insulin Use
1 or more | 250 | 1.68 (1.47–1.93) | 1.48 (1.29–1.70) | 1.44 (1.25–1.66)
1 | 150 | 1.45 (1.23–1.72) | 1.29 (1.10–1.53) | 1.26 (1.10–1.49)
2 | 57 | 2.15 (1.64–2.81) | 1.86 (1.42–2.43) | 1.80 (1.37–2.36)
3 or more | 43 | 2.60 (1.78–3.79) | 2.10 (1.48–2.73) | 1.94 (1.42–2.64)

A1c, glycated hemoglobin; BMI, body mass index.

* Analyses combined using Cox proportional hazard models.

† The 1 or more group is compared to 0. The 3 or more group is compared to 0.

‡ Adjustment made using a comorbidity composite scale.

SOURCE: Reference 126, copyright © 2009 American Medical Association, reproduced with permission. All rights reserved.

### Diabetes Prevention and Cognitive Impairment

The landmark Diabetes Prevention Program Outcomes Study (DPPOS) (128), conducted across 25 sites in the United States, measured cognition during follow-up at two time points 2 years apart (129). The Diabetes Prevention Program, the clinical trial preceding the DPPOS, compared lifestyle and metformin interventions with placebo among 3,234 persons with impaired glucose tolerance and showed that both lifestyle and metformin reduced diabetes incidence compared to placebo. During the DPPOS, participants originally randomized to metformin continued the drug, and a group lifestyle intervention was offered to all. Cognition was assessed (n=2,344) in years 8 and 10 of the DPPOS. Memory was assessed with the Spanish English Verbal Learning Test (SEVLT), the DSST, animal (AF) and letter fluency (LF), and a composite score with z scores of these tests. Cognition was similar across the Diabetes Prevention Program arms in Year 8. However, in mixed models adjusted for age at randomization and assessment year, the composite cognitive score was inversely associated with A1c (p=0.0002), indicating that while the interventions that prevented diabetes were not related to cognitive performance, worse glycemia was related to worse cognitive performance cross-sectionally.

### Diabetes Medications and Cognitive Impairment

As reviewed above, the findings that diabetes is related to an increased risk of AD dementia in epidemiologic studies (113), that peripheral hyperinsulinemia may impair amyloid clearance in the brain (47), and that decreased insulin signaling is a feature of AD brains (130) have prompted the testing of diabetes medications for the treatment or prevention of AD dementia.

The thiazolidinediones are powerful insulin sensitizers used in diabetes treatment (131) and have been tested as possible drugs to prevent or slow dementing processes. The thiazolidinedione rosiglitazone was tested for secondary prevention of cognitive decline in mild AD dementia among 511 persons without diabetes and was found to be nonefficacious (68) after promising results in a pilot study of 30 persons with mild AD dementia and MCI (67). However, it seems possible that the negative vascular effects of rosiglitazone (132) could have eclipsed the beneficial effects on AD pathology (133). The thiazolidinedione pioglitazone seems to have a lower risk of myocardial infarction compared to rosiglitazone (edema and congestive heart failure are class-specific and not lower) (134). However, a trial of pioglitazone in 78 adults with MCI found that pioglitazone improved insulin resistance, but there was no effect on cognitive performance after 6 months (135). It should be noted these drugs have concerning side effects, including edema, congestive heart failure, and in the case of rosiglitazone, myocardial infarction (136). The U.S. Food and Drug Administration issued a warning indicating that rosiglitazone carries cardiovascular risks and restricting its use to patients who cannot control their blood glucose by other means (132).

Metformin, a diabetes medication belonging to the biguanide class (137,138) and the most widely used diabetes medication (139), prevents diabetes by suppressing hepatic glucose output, increasing insulin-mediated glucose disposal, increasing intestinal glucose use, and decreasing fatty acid oxidation (140). These actions are accompanied by reduced pancreatic insulin secretion and lower insulin levels in blood in response to glucose loads. Metformin is usually the first step in pharmacologic treatment of type 2 diabetes (141). There are conflicting data from cell and animal models suggesting that metformin may both increase (142) and decrease (143) AD pathology. Retrospective epidemiologic studies are also conflicting, suggesting that metformin use is associated with both higher (144,145) and lower (146) dementia risk. The DPPOS is the largest study to have examined the effects of metformin among persons with diabetes and those at risk. Metformin exposure over 14.0 years in the DPPOS was not related to cognition (129), suggesting at the very least that it is safe from a cognitive standpoint. A pilot trial of metformin in 80 persons with amnestic MCI without treated diabetes (147) showed that persons in the treatment arm had better memory performance at one year compared with placebo (148). Both the placebo and metformin arms showed improvement in words recalled in a memory test at one year, but the metformin arm showed a significant mean difference of four more words recalled (mean recall at baseline was 34.2 words in the metformin arm and 36.1 in the placebo arm, p=0.32). These results needs to be tested in a larger clinical trial and should be interpreted with caution given the small sample size of the pilot study and the possibility of chance findings. However, these results support those of the DPPOS showing that metformin is at the very least safe from a cognitive standpoint.

Intranasal insulin, used with the purpose of increasing brain insulin (not peripheral insulin), showed preliminary evidence of a cognitive benefit in a pilot study of 25 persons with mild AD dementia (149) randomized to intranasal insulin or placebo. Persons in the treatment group had increased memory savings scores compared to persons in the placebo arm.

The diabetes medication class of glucagon-like peptide agonists (150) increases both insulin secretion and sensitivity and has been hypothesized to be of benefit in AD dementia (151), but this has not been tested in clinical trials.

## Future Directions and Conclusions

An extensive body of research ranging from experimental, clinical, epidemiologic, and patient care studies suggests that diabetes is associated with cognitive impairment from mild to severe forms and including vascular and neurodegenerative forms. The association of diabetes with vascular and non-amnestic forms of cognitive impairment seems to be stronger than that for AD-related and amnestic forms of cognitive impairment. Elucidating the relation between diabetes and cognitive impairment is still an active area of research in many different fields that investigate links among neurodegenerative, vascular, and metabolic processes. Longitudinal studies documenting diabetes onset and cognitive performance at earlier ages than in current studies (most of which use elderly cohorts) are needed. Also important is the development of markers of preclinical cognition that can be used as an outcome in trials of diabetes treatment and prevention. Another important area for more research is the impact of cognitive impairment on diabetes treatment. New reports of an association between diabetes and dementia continue to suggest increased risk of dementia for persons with diabetes. However, the causality of this association has not been established and needs to be further studied. It is possible that processes that underlie both diabetes and AD, such as SorCS1 (152), could explain a link that is not causal. It is also possible that diabetes decreases brain resilience—that is, the brain’s ability to resist neurodegenerative and other brain insults—but does not directly cause AD.

Establishing causality is important because it is necessary to know whether diabetes treatment and prevention strategies can be used to prevent dementia. Also, it is important to know whether Alzheimer’s-based dementia treatment and prevention strategies that are being tested could be useful in persons with diabetes, or whether other strategies should be pursued. In the meantime, the co-occurring epidemics of diabetes and dementia mean that persons with diabetes are very likely to have cognitive impairment that will affect their ability to take care of themselves, which could result in more adverse dementia and diabetes outcomes. This may have a negative impact on health care systems worldwide.

## List of Abbreviations

A1c: glycated hemoglobin
ACCORD-MIND: Action to Control Cardiovascular Risk in Diabetes-Memory in Diabetes study
AD: Alzheimer’s disease
AGE: advanced glycation endproduct
APOE: apolipoprotein E
ARIC: Atherosclerosis Risk in Communities Study
DCCT: Diabetes Control and Complications Trial
DPPOS: Diabetes Prevention Program Outcomes Study
DSST: Digital Symbol Substitution Test
IDEATel: Informatics for Diabetes Education and Telemedicine Study
LDL: low-density lipoprotein
MCI: mild cognitive impairment
PET: positron emission tomography
RAGE: receptor of advanced glycation endproducts
TBV: total brain volume
VCI: vascular cognitive impairment
WMH: white matter hyperintensities

## References

1 Small SA, Mayeux R: A clinical approach to memory decline. J Pract Psychiatry Behav Health 5:87–94, 1999
2 Folstein MF, Folstein SE, McHugh PR: “Mini-mental state”. A practical method for grading the cognitive state of patients for the clinician. J Psychiatr Res 12:189–198, 1975 1202204
3 Royall DR, Lauterbach EC, Cummings JL, Reeve A, Rummans TA, Kaufer DI, LaFrance WC, Jr., Coffey CE: Executive control function: a review of its promise and challenges for clinical research. A report from the Committee on Research of the American Neuropsychiatric Association. J Neuropsychiatry Clin Neurosci 14:377–405, 2002 12426407
4 Wechsler D: Wechsler Memory Scale—Revised Manual. San Antonio, TX, Psychological Corporation, 1987
5 Cohen J: Statistical Power Analysis for the Behavioral Sciences. 2nd ed. Hillsdale, NJ, L. Erlbaum Associates, 1988
6 Luis CA, Loewenstein DA, Acevedo A, Barker WW, Duara R: Mild cognitive impairment: directions for future research. Neurology 61:438–444, 2003 12939414
7 Petersen RC, Smith GE, Waring SC, Ivnik RJ, Tangalos EG, Kokmen E: Mild cognitive impairment: clinical characterization and outcome. Arch Neurol 56:303–308, 1999 10190820
8 Petersen RC, Thomas RG, Grundman M, Bennett D, Doody R, Ferris S, Galasko D, Jin S, Kaye J, Levey A, Pfeiffer E, Sano M, van Dyck CH, Thal LJ; Alzheimer’s Disease Cooperative Study Group: Vitamin E and donepezil for the treatment of mild cognitive impairment. N Engl J Med 352:2379–2388, 2005 15829527
9 Duara R, Loewenstein DA, Greig MT, Potter E, Barker W, Raj A, Schinka J, Borenstein A, Schoenberg M, Wu Y, Banko J, Potter H: Pre-MCI and MCI: neuropsychological, clinical, and imaging features and progression rates. Am J Geriatr Psychiatry 19:951–960, 2011 21422909
10 Luchsinger JA: Insulin resistance, type 2 diabetes, and AD: cerebrovascular disease or neurodegeneration? Neurology 75:758–759, 2010 20739648
11 American Psychiatric Association: Diagnostic and Statistical Manual of Mental Disorders. 5th ed. Arlington, VA, American Psychiatric Publishing, 2013
12 Alzheimer’s Association: 2014 Alzheimer’s disease facts and figures. Alzheimers Dement 10:e47–e92, 2014 24818261
13 Chui HC, Mack W, Jackson JE, Mungas D, Reed BR, Tinklenberg J, Chang FL, Skinner K, Tasaki C, Jagust WJ: Clinical criteria for the diagnosis of vascular dementia: a multicenter study of comparability and interrater reliability. Arch Neurol 57:191–196, 2000 10681076
14 Boden-Albala B, Cammack S, Chong J, Wang C, Wright C, Rundek T, Elkind MS, Paik MC, Sacco RL: Diabetes, fasting glucose levels, and risk of ischemic stroke and vascular events: findings from the Northern Manhattan Study (NOMAS). Diabetes Care 31:1132–1137, 2008 18339972
15 Alzheimer’s Association: 2011 Alzheimer’s disease facts and figures. Alzheimers Dement 7:208–244, 2011 21414557
16 Seshadri S, Wolf PA, Beiser A, Au R, McNulty K, White R, D’Agostino RB: Lifetime risk of dementia and Alzheimer’s disease. The impact of mortality on risk estimates in the Framingham Study. Neurology 49:1498–1504, 1997 9409336
17 Evans DA, Funkenstein HH, Albert MS, Scherr PA, Cook NR, Chown MJ, Hebert LE, Hennekens CH, Taylor JO: Prevalence of Alzheimer’s disease in a community population of older persons. Higher than previously reported. JAMA 262:2551–2556, 1989 2810583
18 Hebert LE, Weuve J, Scherr PA, Evans DA: Alzheimer disease in the United States (2010–2050) estimated using the 2010 census. Neurology 80:1778–1783, 2013 23390181
19 Busse A, Bischkopf J, Riedel-Heller SG, Angermeyer MC: Mild cognitive impairment: prevalence and incidence according to different diagnostic criteria. Results of the Leipzig Longitudinal Study of the Aged (LEILA75+). Br J Psychiatry 182:449–454, 2003 12724250
20 Yesavage JA, O’Hara R, Kraemer H, Noda A, Taylor JL, Ferris S, Gely-Nargeot MC, Rosen A, Friedman L, Sheikh J, Derouesne C: Modeling the prevalence and incidence of Alzheimer’s disease and mild cognitive impairment. J Psychiatr Res 36:281–286, 2002 12127595
21 Plassman BL, Langa KM, Fisher GG, Heeringa SG, Weir DR, Ofstedal MB, Burke JR, Hurd MD, Potter GG, Rodgers WL, Steffens DC, McArdle JJ, Willis RJ, Wallace RB: Prevalence of cognitive impairment without dementia in the United States. Ann Intern Med 148:427–434, 2008 18347351
22 Centers for Disease Control and Prevention: National Diabetes Fact Sheet: National Estimates and General Information on Diabetes and Prediabetes in the United States, 2011. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, 2011
23 Press release: number of people with diabetes increases to 24 million [article online], 2008. Available from http://www.cdc.gov/media/pressrel/2008/r080624.htm. Accessed 27 June 2008
24 Harris MI, Flegal KM, Cowie CC, Eberhardt MS, Goldstein DE, Little RR, Wiedmeyer HM, Byrd-Holt DD: Prevalence of diabetes, impaired fasting glucose, and impaired glucose tolerance in U.S. adults. The Third National Health and Nutrition Examination Survey, 1988–1994. Diabetes Care 21:518–524, 1998 9571335
25 Luchsinger JA: Diabetes. In Health Issues in the Latino Community. Aguirre-Molina M, Molina CW, Zambrana RE, Eds. San Francisco, Jossey-Bass, 2001, p. 277–300
26 Luchsinger JA, Tang MX, Stern Y, Shea S, Mayeux R: Diabetes mellitus and risk of Alzheimer’s disease and dementia with stroke in a multiethnic cohort. Am J Epidemiol 154:635–641, 2001 11581097
27 Tang MX, Stern Y, Marder K, Bell K, Gurland B, Lantigua R, Andrews H, Feng L, Tycko B, Mayeux R: The APOE-epsilon4 allele and the risk of Alzheimer disease among African Americans, whites, and Hispanics. JAMA 279:751–755, 1998 9508150
28 Noble JM, Manly JJ, Schupf N, Tang MX, Luchsinger JA: Type 2 diabetes and ethnic disparities in cognitive impairment. Ethn Dis 22:38–44, 2012 22774307
29 Cummings JL: Alzheimer’s disease. N Engl J Med 351:56–67, 2004 15229308
30 Selkoe DJ: The origins of Alzheimer disease: a is for amyloid. JAMA 283:1615–1617, 2000 10735401
31 Daviglus ML, Bell CC, Berrettini W, Bowen PE, Connolly ES, Jr., Cox NJ, Dunbar-Jacob JM, Granieri EC, Hunt G, McGarry K, Patel D, Potosky AL, Sanders-Bush E, Silberberg D, Trevisan M: NIH state-of-the-science conference statement: preventing Alzheimer’s disease and cognitive decline. NIH Consens State Sci Statements 27:1–30, 2010
32 Selkoe DJ: Alzheimer’s disease: genotypes, phenotypes, and treatments. Science 275:630–631, 1997 9019820
33 Green RC, Roberts JS, Cupples LA, Relkin NR, Whitehouse PJ, Brown T, Eckert SL, Butson M, Sadovnick AD, Quaid KA, Chen C, Cook-Deegan R, Farrer LA; REVEAL Study Group: Disclosure of APOE genotype for risk of Alzheimer’s disease. N Engl J Med 361:245–254, 2009 19605829
34 Caselli RJ, Dueck AC, Osborne D, Sabbagh MN, Connor DJ, Ahern GL, Baxter LC, Rapcsak SZ, Shi J, Woodruff BK, Locke DE, Snyder CH, Alexander GE, Rademakers R, Reiman EM: Longitudinal modeling of age-related memory decline and the APOE epsilon4 effect. N Engl J Med 361:255–263, 2009 19605830
35 Mayeux R, Saunders AM, Shea S, Mirra S, Evans D, Roses AD, Hyman BT, Crain B, Tang MX, Phelps CH: Utility of the apolipoprotein E genotype in the diagnosis of Alzheimer’s disease. Alzheimer’s Disease Centers Consortium on Apolipoprotein E and Alzheimer’s Disease. N Engl J Med 338:506–511, 1998 9468467
36 Luchsinger JA: The relationship between the continuum of elevated adiposity, hyperinsulinemia, and type 2 diabetes and late onset Alzheimer’s disease: an epidemiologic perspective. In Diabetes, Insulin, and Alzheimer’s Disease. Craft S, Christen Y, Eds. Berlin Heidelberg, Springer, 2010, p. 89–107
37 Reitz C, Tang MX, Manly J, Mayeux R, Luchsinger JA: Hypertension and the risk of mild cognitive impairment. Arch Neurol 64:1734–1740, 2007 18071036
38 Posner HB, Tang MX, Luchsinger J, Lantigua R, Stern Y, Mayeux R: The relationship of hypertension in the elderly to AD, vascular dementia, and cognitive function. Neurology 58:1175–1181, 2002 11971083
39 Gorelick PB, Scuteri A, Black SE, Decarli C, Greenberg SM, Iadecola C, Launer LJ, Laurent S, Lopez OL, Nyenhuis D, Petersen RC, Schneider JA, Tzourio C, Arnett DK, Bennett DA, Chui HC, Higashida RT, Lindquist R, Nilsson PM, Roman GC, Sellke FW, Seshadri S; American Heart Association Stroke Council; Council on Epidemiology and Prevention; Council on Cardiovascular Nursing; Council on Cardiovascular Radiology and Intervention; and Council on Cardiovascular Surgery and Anesthesia: Vascular contributions to cognitive impairment and dementia: a statement for healthcare professionals from the American Heart Association/American Stroke Association. Stroke 42:2672–2713, 2011 21778438
40 Hachinski V, Iadecola C, Petersen RC, Breteler MM, Nyenhuis DL, Black SE, Powers WJ, DeCarli C, Merino JG, Kalaria RN, Vinters HV, Holtzman DM, Rosenberg GA, Wallin A, Dichgans M, Marler JR, Leblanc GG: National Institute of Neurological Disorders and Stroke-Canadian Stroke Network vascular cognitive impairment harmonization standards. Stroke 37:2220–2241, 2006 16917086
41 Benson RT, Sacco RL: Stroke prevention: hypertension, diabetes, tobacco, and lipids. Neurol Clin 18:309–319, 2000 10757828
42 Grundy SM, Cleeman JI, Daniels SR, Donato KA, Eckel RH, Franklin BA, Gordon DJ, Krauss RM, Savage PJ, Smith SC, Jr., Spertus JA, Costa F; American Heart Association; National Heart, Lung, and Blood Institute: Diagnosis and management of the metabolic syndrome: an American Heart Association/National Heart, Lung, and Blood Institute scientific statement. Circulation 112:2735–2752, 2005 16157765
43 Suk SH, Sacco RL, Boden-Albala B, Cheun JF, Pittman JG, Elkind MS, Paik MC; Northern Manhattan Stroke Study: Abdominal obesity and risk of ischemic stroke: the Northern Manhattan Stroke Study. Stroke 34:1586–1592, 2003 12775882
44 Sacco RL: Reducing the risk of stroke in diabetes: what have we learned that is new? Diabetes Obes Metab 4(Suppl 1):S27–S34, 2002 11843952
45 Sacco RL, Benson RT, Kargman DE, Boden-Albala B, Tuck C, Lin IF, Cheng JF, Paik MC, Shea S, Berglund L: High-density lipoprotein cholesterol and ischemic stroke in the elderly: the Northern Manhattan Stroke Study. JAMA 285:2729–2735, 2001 11386928
46 Boden-Albala B, Sacco RL: Lifestyle factors and stroke risk: exercise, alcohol, diet, obesity, smoking, drug use, and stress. Curr Atheroscler Rep 2:160–166, 2000 11122740
47 Craft S, Watson GS: Insulin and neurodegenerative disease: shared and specific mechanisms. Lancet Neurol 3:169–178, 2004 14980532
48 Honig LS, Tang MX, Albert S, Costa R, Luchsinger J, Manly J, Stern Y, Mayeux R: Stroke and the risk of Alzheimer disease. Arch Neurol 60:1707–1712, 2003 14676044
49 Vermeer SE, Prins ND, den Heijer T, Hofman A, Koudstaal PJ, Breteler MM: Silent brain infarcts and the risk of dementia and cognitive decline. N Engl J Med 348:1215–1222, 2003 12660385
50 Snowdon DA, Greiner LH, Mortimer JA, Riley KP, Greiner PA, Markesbery WR: Brain infarction and the clinical expression of Alzheimer disease. The Nun Study. JAMA 277:813–817, 1997 9052711
51 Schneider JA, Arvanitakis Z, Bang W, Bennett DA: Mixed brain pathologies account for most dementia cases in community-dwelling older persons. Neurology 69:2197–2204, 2007 17568013
52 Pantoni L: White matter ischemia: time to begin integrating experimental and clinical data. Eur Neurol 56:71–73, 2006 16946617
53 Nakata-Kudo Y, Mizuno T, Yamada K, Shiga K, Yoshikawa K, Mori S, Nishimura T, Nakajima K, Nakagawa M: Microbleeds in Alzheimer disease are more related to cerebral amyloid angiopathy than cerebrovascular disease. Dement Geriatr Cogn Disord 22:8–14, 2006 16645275
54 Haglund M, Englund E: Cerebral amyloid angiopathy, white matter lesions and Alzheimer encephalopathy—a histopathological assessment. Dement Geriatr Cogn Disord 14:161–166, 2002 12218260
55 Gurol ME, Irizarry MC, Smith EE, Raju S, Diaz-Arrastia R, Bottiglieri T, Rosand J, Growdon JH, Greenberg SM: Plasma beta-amyloid and white matter lesions in AD, MCI, and cerebral amyloid angiopathy. Neurology 66:23–29, 2006 16401840
56 Alonzo NC, Hyman BT, Rebeck GW, Greenberg SM: Progression of cerebral amyloid angiopathy: accumulation of amyloid-beta40 in affected vessels. J Neuropathol Exp Neurol 57:353–359, 1998 9600229
57 Manschot SM, Brands AM, van der Grond J, Kessels RP, Algra A, Kappelle LJ, Biessels GJ; Utrecht Diabetic Encephalopathy Study Group: Brain magnetic resonance imaging correlates of impaired cognition in patients with type 2 diabetes. Diabetes 55:1106–1113, 2006 16567535
58 Reaven G: Insulin resistance, type 2 diabetes mellitus, and cardiovascular disease: the end of the beginning. Circulation 112:3030–3032, 2005 16286599
59 Festa A, Williams K, D’Agostino R, Jr., Wagenknecht LE, Haffner SM: The natural course of beta-cell function in nondiabetic and diabetic individuals: the Insulin Resistance Atherosclerosis Study. Diabetes 55:1114–1120, 2006 16567536
60 Park CR: Cognitive effects of insulin in the central nervous system. Neurosci Biobehav Rev 25:311–323, 2001 11445137
61 Watson GS, Peskind ER, Asthana S, Purganan K, Wait C, Chapman D, Schwartz MW, Plymate S, Craft S: Insulin increases CSF Abeta42 levels in normal older adults. Neurology 60:1899–1903, 2003 12821730
62 Small SA, Perera GM, DeLaPaz R, Mayeux R, Stern Y: Differential regional dysfunction of the hippocampal formation among elderly with memory decline and Alzheimer’s disease. Ann Neurol 45:466–472, 1999 10211471
63 Farris W, Mansourian S, Chang Y, Lindsley L, Eckman EA, Frosch MP, Eckman CB, Tanzi RE, Selkoe DJ, Guenette S: Insulin-degrading enzyme regulates the levels of insulin, amyloid beta-protein, and the beta-amyloid precursor protein intracellular domain in vivo. Proc Natl Acad Sci U S A 100:4162–4167, 2003 12634421
64 Craft S: Insulin resistance and Alzheimer’s disease pathogenesis: potential mechanisms and implications for treatment. Curr Alzheimer Res 4:147–152, 2007 17430239
65 Banks WA, Jaspan JB, Huang W, Kastin AJ: Transport of insulin across the blood-brain barrier: saturability at euglycemic doses of insulin. Peptides 18:1423–1429, 1997 9392846
66 Zhao L, Teter B, Morihara T, Lim GP, Ambegaokar SS, Ubeda OJ, Frautschy SA, Cole GM: Insulin-degrading enzyme as a downstream target of insulin receptor signaling cascade: implications for Alzheimer’s disease intervention. J Neurosci 24:11120–11126, 2004 15590928
67 Watson GS, Cholerton BA, Reger MA, Baker LD, Plymate SR, Asthana S, Fishel MA, Kulstad JJ, Green PS, Cook DG, Kahn SE, Keeling ML, Craft S: Preserved cognition in patients with early Alzheimer disease and amnestic mild cognitive impairment during treatment with rosiglitazone: a preliminary study. Am J Geriatr Psychiatry 13:950–958, 2005 16286438
68 Risner ME, Saunders AM, Altman JF, Ormandy GC, Craft S, Foley IM, Zvartau-Hind ME, Hosford DA, Roses AD; Rosiglitazone in Alzheimer’s Disease Study Group: Efficacy of rosiglitazone in a genetically defined population with mild-to-moderate Alzheimer’s disease. Pharmacogenomics J 6:246–254, 2006 16446752
69 Reger MA, Watson GS, Frey WH 2nd, Baker LD, Cholerton B, Keeling ML, Belongia DA, Fishel MA, Plymate SR, Schellenberg GD, Cherrier MM, Craft S: Effects of intranasal insulin on cognition in memory-impaired older adults: modulation by APOE genotype. Neurobiol Aging 27:451–458, 2006 15964100
70 Goldin A, Beckman JA, Schmidt AM, Creager MA: Advanced glycation end products: sparking the development of diabetic vascular injury. Circulation 114:597–605, 2006 16894049
71 Basta G, Schmidt AM, De Caterina R: Advanced glycation end products and vascular inflammation: implications for accelerated atherosclerosis in diabetes. Cardiovasc Res 63:582–592, 2004 15306213
72 Negrean M, Stirban A, Stratmann B, Gawlowski T, Horstmann T, Gotting C, Kleesiek K, Mueller-Roesel M, Koschinsky T, Uribarri J, Vlassara H, Tschoepe D: Effects of low- and high-advanced glycation endproduct meals on macro-and microvascular endothelial function and oxidative stress in patients with type 2 diabetes mellitus. Am J Clin Nutr 85:1236–1243, 2007 17490958
73 Vlassara H, Striker LJ, Teichberg S, Fuh H, Li YM, Steffes M: Advanced glycation end products induce glomerular sclerosis and albuminuria in normal rats. Proc Natl Acad Sci U S A 91:11704–11708, 1994 7972128
74 Peppa M, Brem H, Cai W, Zhang JG, Basgen J, Li Z, Vlassara H, Uribarri J: Prevention and reversal of diabetic nephropathy in db/db mice treated with alagebrium (ALT-711). Am J Nephrol 26:430–436, 2006 16974073
75 Thallas-Bonke V, Lindschau C, Rizkalla B, Bach LA, Boner G, Meier M, Haller H, Cooper ME, Forbes JM: Attenuation of extracellular matrix accumulation in diabetic nephropathy by the advanced glycation end product cross-link breaker ALT-711 via a protein kinase C-alpha-dependent pathway. Diabetes 53:2921–2930, 2004 15504973
76 Stitt AW: Advanced glycation: an important pathological event in diabetic and age related ocular disease. Br J Ophthalmol 85:746–753, 2001 11371498
77 Schalkwijk CG, Lieuw-a-Fa M, van Hinsbergh VW, Stehouwer CD: Pathophysiological role of Amadori-glycated proteins in diabetic microangiopathy. Semin Vasc Med 2:191–197, 2002 16222610
78 Sullivan KA, Feldman EL: New developments in diabetic neuropathy. Curr Opin Neurol 18:586–590, 2005 16155445
79 Yan SD, Chen X, Fu J, Chen M, Zhu H, Roher A, Slattery T, Zhao L, Nagashima M, Morser J, Migheli A, Nawroth P, Stern D, Schmidt AM: RAGE and amyloid-beta peptide neurotoxicity in Alzheimer’s disease. Nature 382:685–691, 1996 8751438
80 Schmidt AM, Yan SD, Yan SF, Stern DM: The biology of the receptor for advanced glycation end products and its ligands. Biochim Biophys Acta 1498:99–111, 2000 11108954
81 Lue LF, Walker DG, Brachova L, Beach TG, Rogers J, Schmidt AM, Stern DM, Yan SD: Involvement of microglial receptor for advanced glycation endproducts (RAGE) in Alzheimer’s disease: identification of a cellular activation mechanism. Exp Neurol 171:29–45, 2001 11520119
82 Deane R, Du Yan S, Submamaryan RK, LaRue B, Jovanovic S, Hogg E, Welch D, Manness L, Lin C, Yu J, Zhu H, Ghiso J, Frangione B, Stern A, Schmidt AM, Armstrong DL, Arnold B, Liliensiek B, Nawroth P, Hofman F, Kindy M, Stern D, Zlokovic B: RAGE mediates amyloid-beta peptide transport across the blood-brain barrier and accumulation in brain. Nat Med 9:907–913, 2003 12808450
83 Arvanitakis Z, Schneider JA, Wilson RS, Li Y, Arnold SE, Wang Z, Bennett DA: Diabetes is related to cerebral infarction but not to AD pathology in older persons. Neurology 67:1960–1965, 2006 17159101
84 Beeri MS, Silverman JM, Davis KL, Marin D, Grossman HZ, Schmeidler J, Purohit DP, Perl DP, Davidson M, Mohs RC, Haroutunian V: Type 2 diabetes is negatively associated with Alzheimer’s disease neuropathology. J Gerontol A Biol Sci Med Sci 60:471–475, 2005 15933386
85 Ahtiluoto S, Polvikoski T, Peltonen M, Solomon A, Tuomilehto J, Winblad B, Sulkava R, Kivipelto M: Diabetes, Alzheimer disease, and vascular dementia: a population-based neuropathologic study. Neurology 75:1195–1202, 2010 20739645
86 Peila R, Rodriguez BL, Launer LJ; Honolulu-Asia Aging Study: Type 2 diabetes, APOE gene, and the risk for dementia and related pathologies: the Honolulu-Asia Aging Study. Diabetes 51:1256–1262, 2002 11916953
87 Matsuzaki T, Sasaki K, Tanizaki Y, Hata J, Fujimi K, Matsui Y, Sekita A, Susuki O, Kanba S, Kiyohara Y, Iwaki T: Insulin resistance is associated with the pathology of Alzheimer disease: the Hisayama study. Neurology 75:764–770, 2010 20739649
88 Baker LD, Cross DJ, Minoshima S, Belongia D, Watson GS, Craft S: Insulin resistance and Alzheimer-like reductions in regional cerebral glucose metabolism for cognitively normal adults with prediabetes or early type 2 diabetes. Arch Neurol 68:51–57, 2011 20837822
89 Roberts RO, Knopman DS, Cha RH, Mielke MM, Pankratz VS, Boeve BF, Kantarci K, Geda YE, Jack CR, Jr., Petersen RC, Lowe VJ: Diabetes and elevated hemoglobin A1c levels are associated with brain hypometabolism but not amyloid accumulation. J Nucl Med 55:759–764, 2014 24652830
90 Thambisetty M, Jeffrey Metter E, Yang A, Dolan H, Marano C, Zonderman AB, Troncoso JC, Zhou Y, Wong DF, Ferrucci L, Egan J, Resnick SM, O’Brien RJ: Glucose intolerance, insulin resistance, and pathological features of Alzheimer disease in the Baltimore Longitudinal Study of Aging. JAMA Neurol 70:1167–1172, 2013 23897112
91 Neuropsychological Assessment. 4th Ed. Lezak MD, Howieson DB, Loring DW, Eds. New York, NY, Oxford University Press, 2004
92 Strauss E, Sherman EMS, Spreen O: A Compendium of Neuropsychological Tests: Administration, Norms, and Commentary. 3rd ed. New York, NY, Oxford University Press, 2006
93 Cohen J: A power primer. Psychol Bull 112:155–159, 1992 19565683
94 Ryan C, Vega A, Drash A: Cognitive deficits in adolescents who developed diabetes early in life. Pediatrics 75:921–927, 1985 3991281
95 Effects of intensive diabetes therapy on neuropsychological function in adults in the Diabetes Control and Complications Trial. Ann Intern Med 124:379–388, 1996 8554246
96 Gaudieri PA, Chen R, Greer TF, Holmes CS: Cognitive function in children with type 1 diabetes: a meta-analysis. Diabetes Care 31:1892–1897, 2008 18753668
97 Ryan CM: Why is cognitive dysfunction associated with the development of diabetes early in life? The diathesis hypothesis. Pediatr Diabetes 7:289–297, 2006 17054452
98 Naguib JM, Kulinskaya E, Lomax CL, Garralda ME: Neuro-cognitive performance in children with type 1 diabetes—a meta-analysis. J Pediatr Psychol 34:271–282, 2009 18635605
99 Brands AM, Biessels GJ, De Haan EH, Kappelle LJ, Kessels RP: The effects of type 1 diabetes on cognitive performance: a meta-analysis. Diabetes Care 28:726–735, 2005 15735218
100 Retinopathy and nephropathy in patients with type 1 diabetes four years after a trial of intensive therapy. The Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Research Group. N Engl J Med 342:381–389, 2000 10666428
101 Austin EJ, Deary IJ: Effects of repeated hypoglycemia on cognitive function: a psychometrically validated reanalysis of the Diabetes Control and Complications Trial data. Diabetes Care 22:1273–1277, 1999 10480770
102 A screening algorithm to identify clinically significant changes in neuropsychological functions in the Diabetes Control and Complications Trial. DCCT Research Group. J Clin Exp Neuropsychol 16:303–316, 1994 8021316
103 Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Study Research Group; Jacobson AM, Musen G, Ryan CM, Silvers N, Cleary P, Waberski B, Burwood A, Weinger K, Bayless M, Dahms W, Harth J: Long-term effects of diabetes and its treatment on cognitive function. N Engl J Med 356:1842–1852, 2007 17476010
104 Jacobson AM, Ryan CM, Cleary PA, Waberski BH, Weinger K, Musen G, Dahms W; Diabetes Control and Complications Trial/EDIC Research Group: Biomedical risk factors for decreased cognitive functioning in type 1 diabetes: an 18 year follow-up of the Diabetes Control and Complications Trial (DCCT) cohort. Diabetologia 54:245–255, 2011 20803190
105 Ryan CM, Geckle MO, Orchard TJ: Cognitive efficiency declines over time in adults with type 1 diabetes: effects of micro- and macrovascular complications. Diabetologia 46:940–948, 2003 12819900
106 Kanaya AM, Barrett-Connor E, Gildengorin G, Yaffe K: Change in cognitive function by glucose tolerance status in older adults: a 4-year prospective study of the Rancho Bernardo study cohort. Arch Intern Med 164:1327–1333, 2004 15226167
107 Knopman D, Boland LL, Mosley T, Howard G, Liao D, Szklo M, McGovern P, Folsom AR; Atherosclerosis Risk in Communities (ARIC) Study Investigators: Cardiovascular risk factors and cognitive decline in middle-aged adults. Neurology 56:42–48, 2001 11148234
108 Yaffe K, Blackwell T, Kanaya AM, Davidowitz N, Barrett-Connor E, Krueger K: Diabetes, impaired fasting glucose, and development of cognitive impairment in older women. Neurology 63:658–663, 2004 15326238
109 MacKnight C, Rockwood K, Awalt E, McDowell I: Diabetes mellitus and the risk of dementia, Alzheimer’s disease and vascular cognitive impairment in the Canadian Study of Health and Aging. Dement Geriatr Cogn Disord 14:77–83, 2002 12145454
110 Luchsinger JA, Reitz C, Patel B, Tang MX, Manly JJ, Mayeux R: Relation of diabetes to mild cognitive impairment. Arch Neurol 64:570–575, 2007 17420320
111 Roberts RO, Geda YE, Knopman DS, Christianson TJ, Pankratz VS, Boeve BF, Vella A, Rocca WA, Petersen RC: Association of duration and severity of diabetes mellitus with mild cognitive impairment. Arch Neurol 65:1066–1073, 2008 18695056
112 Biessels GJ, Strachan MW, Visseren FL, Kappelle LJ, Whitmer RA: Dementia and cognitive decline in type 2 diabetes and prediabetic stages: towards targeted interventions. Lancet Diabetes Endocrinol 2:246–255, 2014 24622755
113 Biessels GJ, Staekenborg S, Brunner E, Brayne C, Scheltens P: Risk of dementia in diabetes mellitus: a systematic review. Lancet Neurol 5:64–74, 2006 16361024
114 Crane PK, Walker R, Hubbard RA, Li G, Nathan DM, Zheng H, Haneuse S, Craft S, Montine TJ, Kahn SE, McCormick W, McCurry SM, Bowen JD, Larson EB: Glucose levels and risk of dementia. N Engl J Med 369:540–548, 2013 23924004
115 Irie F, Fitzpatrick AL, Lopez OL, Kuller LH, Peila R, Newman AB, Launer LJ: Enhanced risk for Alzheimer disease in persons with type 2 diabetes and APOE epsilon4: the Cardiovascular Health Study Cognition Study. Arch Neurol 65:89–93, 2008 18195144
116 Launer LJ, Miller ME, Williamson JD, Lazar RM, Gerstein HC, Murray AM, Sullivan M, Horowitz KR, Ding J, Marcovina S, Lovato LC, Lovato J, Margolis KL, O’Connor P, Lipkin EW, Hirsch J, Coker L, Maldjian J, Sunshine JL, Truwit C, Davatzikos C, Bryan RN; ACCORD MIND Investigators: Effects of intensive glucose lowering on brain structure and function in people with type 2 diabetes (ACCORD MIND): a randomised open-label substudy. Lancet Neurol 10:969–977, 2011 21958949
117 Cukierman-Yaffe T, Gerstein HC, Williamson JD, Lazar RM, Lovato L, Miller ME, Coker LH, Murray A, Sullivan MD, Marcovina SM, Launer LJ; Action to Control Cardiovascular Risk in Diabetes-Memory in Diabetes (ACCORD-MIND) Investigators: Relationship between baseline glycemic control and cognitive function in individuals with type 2 diabetes and other cardiovascular risk factors: the Action to Control Cardiovascular Risk in Diabetes-Memory in Diabetes (ACCORD-MIND) trial. Diabetes Care 32:221–226, 2009 19171735
118 Sullivan MD, Katon WJ, Lovato LC, Miller ME, Murray AM, Horowitz KR, Bryan RN, Gerstein HC, Marcovina S, Akpunonu BE, Johnson J, Yale JF, Williamson J, Launer LJ: Association of depression with accelerated cognitive decline among patients with type 2 diabetes in the ACCORD-MIND trial. JAMA Psychiatry 70:1041–1047, 2013 23945905
119 Shea S, Starren J, Weinstock RS, Knudson PE, Teresi J, Holmes D, Palmas W, Field L, Goland R, Tuck C, Hripcsak G, Capps L, Liss D: Columbia University’s Informatics for Diabetes Education and Telemedicine (IDEATel) Project: rationale and design. J Am Med Inform Assoc 9:49–62, 2002 11751803
120 Shea S, Weinstock RS, Teresi JA, Palmas W, Starren J, Cimino JJ, Lai AM, Field L, Morin PC, Goland R, Izquierdo RE, Ebner S, Silver S, Petkova E, Kong J, Eimicke JP; IDEATel Consortium: A randomized trial comparing telemedicine case management with usual care in older, ethnically diverse, medically underserved patients with diabetes mellitus: 5 year results of the IDEATel study. J Am Med Inform Assoc 16:446–456, 2009 19390093
121 Luchsinger JA, Palmas W, Teresi JA, Silver S, Kong J, Eimicke JP, Weinstock RS, Shea S: Improved diabetes control in the elderly delays global cognitive decline. J Nutr Health Aging 15:445–449, 2011 21623465
122 Action to Control Cardiovascular Risk in Diabetes Study Group; Gerstein HC, Miller ME, Byington RP, Goff DC, Jr., Bigger JT, Buse JB, Cushman WC, Genuth S, Ismail-Beigi F, Grimm RH, Jr., Probstfield JL, Simons-Morton DG, Friedewald WT: Effects of intensive glucose lowering in type 2 diabetes. N Engl J Med 358:2545–2559, 2008 18539917
123 Palta P, Golden SH, Teresi J, Palmas W, Weinstock RS, Shea S, Manly JJ, Luchsinger JA: Mild cognitive dysfunction does not affect diabetes mellitus control in minority elderly adults. J Am Geriatr Soc 62:2363–2368, 2014 25439094
124 Espeland MA, Rapp SR, Bray GA, Houston DK, Johnson KC, Kitabchi AE, Hergenroeder AL, Williamson J, Jakicic JM, van Dorsten B, Kritchevsky SB; Action for Health In Diabetes (Look AHEAD) Movement and Memory Subgroup; Look AHEAD Research Group: Long-term impact of behavioral weight loss intervention on cognitive function. J Gerontol A Biol Sci Med Sci 69:1101–1108, 2014 24619151
125 Look AHEAD Research Group; Pi-Sunyer X, Blackburn G, Brancati FL, Bray GA, Bright R, Clark JM, Curtis JM, Espeland MA, Foreyt JP, Graves K, Haffner SM, Harrison B, Hill JO, Horton ES, Jakicic J, Jeffery RW, Johnson KC, Kahn S, Kelley DE, Kitabchi AE, Knowler WC, Lewis CE, Maschak-Carey BJ, Montgomery B, Nathan DM, Patricio J, Peters A, Redmon JB, Reeves RS, Ryan DH, Safford M, Van Dorsten B, Wadden TA, Wagenknecht L, Wesche-Thobaben J, Wing RR, Yanovski SZ: Reduction in weight and cardiovascular disease risk factors in individuals with type 2 diabetes: one-year results of the Look AHEAD trial. Diabetes Care 30:1374–1383, 2007 17363746
126 Whitmer RA, Karter AJ, Yaffe K, Quesenberry CP, Jr., Selby JV: Hypoglycemic episodes and risk of dementia in older patients with type 2 diabetes mellitus. JAMA 301:1565–1572, 2009 19366776
127 Punthakee Z, Miller ME, Launer LJ, Williamson JD, Lazar RM, Cukierman-Yaffee T, Seaquist ER, Ismail-Beigi F, Sullivan MD, Lovato LC, Bergenstal RM, Gerstein HC; ACCORD Group of Investigators; ACCORD-MIND Investigators: Poor cognitive function and risk of severe hypoglycemia in type 2 diabetes: post hoc epidemiologic analysis of the ACCORD trial. Diabetes Care 35:787–793, 2012 22374637
128 Diabetes Prevention Program Research Group; Knowler WC, Fowler SE, Hamman RF, Christophi CA, Hoffman HJ, Brenneman AT, Brown-Friday JO, Goldberg R, Venditti E, Nathan DM: 10-year follow-up of diabetes incidence and weight loss in the Diabetes Prevention Program Outcomes Study. Lancet 374:1677–1686, 2009 19878986
129 Luchsinger JA, Ma Y, Florez H, Manly JJ, Golden SH, Hazuda H, Crandall J, Venditti EM, Watson K, Jeffries S, Pi-Sunyer X: Cognition in the Diabetes Prevention Program Outcomes Study (DPPOS). Diabetes 63(Suppl 1):A88, 2014
130 de la Monte SM, Wands JR: Alzheimer’s disease is type 3 diabetes—evidence reviewed. J Diabetes Sci Technol 2:1101–1113, 2008 19885299
131 Yki-Jarvinen H: Thiazolidinediones. N Engl J Med 351:1106–1118, 2004 15356308
132 Nathan DM: Rosiglitazone and cardiotoxicity—weighing the evidence. N Engl J Med 357:64–66, 2007 17551161
133 Luchsinger JA: Type 2 diabetes, related conditions, in relation and dementia: an opportunity for prevention? J Alzheimers Dis 20:723–736, 2010 20413862
134 Lincoff AM, Wolski K, Nicholls SJ, Nissen SE: Pioglitazone and risk of cardiovascular events in patients with type 2 diabetes mellitus: a meta-analysis of randomized trials. JAMA 298:1180–1188, 2007 17848652
135 Hildreth KL, Van Pelt RE, Moreau KL, Grigsby J, Hoth KF, Pelak V, Anderson CA, Parnes B, Kittelson J, Wolfe P, Nakamura T, Linnebur SA, Trujillo JM, Aquilante CL, Schwartz RS: Effects of pioglitazone or exercise in older adults with mild cognitive impairment and insulin resistance: a pilot study. Dement Geriatr Cogn Dis Extra 5:51–63, 2015 25852732
136 Nathan DM, Berkwits M: Trials that matter: rosiglitazone, ramipril, and the prevention of type 2 diabetes. Ann Intern Med 146:461–463, 2007 17371892
137 Bailey CJ, Turner RC: Metformin. N Engl J Med 334:574–579, 1996 8569826
138 Dunn CJ, Peters DH: Metformin. A review of its pharmacological properties and therapeutic use in non-insulin-dependent diabetes mellitus. Drugs 49:721–749, 1995 7601013
139 Ferrannini E: The target of metformin in type 2 diabetes. N Engl J Med 371:1547–1548, 2014 25317875
140 Tian J, Shi J, Bailey K, Lendon CL, Pickering-Brown SM, Mann DM: Association between apolipoprotein E e4 allele and arteriosclerosis, cerebral amyloid angiopathy, and cerebral white matter damage in Alzheimer’s disease. J Neurol Neurosurg Psychiatry 75:696–699, 2004 15090562
141 Nathan DM: Clinical practice. Initial management of glycemia in type 2 diabetes mellitus. N Engl J Med 347:1342–1349, 2002 12397193
142 Chen Y, Zhou K, Wang R, Liu Y, Kwak YD, Ma T, Thompson RC, Zhao Y, Smith L, Gasparini L, Luo Z, Xu H, Liao FF: Antidiabetic drug metformin (GlucophageR) increases biogenesis of Alzheimer’s amyloid peptides via up-regulating BACE1 transcription. Proc Natl Acad Sci U S A 106:3907–3912, 2009 19237574
143 Gupta A, Bisht B, Dey CS: Peripheral insulin-sensitizer drug metformin ameliorates neuronal insulin resistance and Alzheimer’s-like changes. Neuropharmacology 60:910–920, 2011 21277873
144 Imfeld P, Bodmer M, Jick SS, Meier CR: Metformin, other antidiabetic drugs, and risk of Alzheimer’s disease: a population-based case-control study. J Am Geriatr Soc 60:916–921, 2012 22458300
145 Moore EM, Mander AG, Ames D, Kotowicz MA, Carne RP, Brodaty H, Woodward M, Boundy K, Ellis KA, Bush AI, Faux NG, Martins R, Szoeke C, Rowe C, Watters DA; AIBL Investigators: Increased risk of cognitive impairment in patients with diabetes is associated with metformin. Diabetes Care 36:2981–2987, 2013 24009301
146 Hsu CC, Wahlqvist ML, Lee MS, Tsai HN: Incidence of dementia is increased in type 2 diabetes and reduced by the use of sulfonylureas and metformin. J Alzheimers Dis 24:485–493, 2011 21297276
147 Perez T, Thareja S, Arana E, Chang H, Bagiela E, Luchsinger JA: Phase II clinical trial of metformin in amnestic MCI: rationale, methods, and barriers and enablers of successful recruitment. J Nutr Health Aging 15(Suppl 1):S14, 2011
148 Luchsinger JA, Perez T, Chang H, Mehta P, Steffener J, Pradabhan G, Ichise M, Manly J, Devanand D, Bagiella E: Metformin in amnestic mild cognitive impairment: results of a pilot randomized placebo controlled clinical trial. J Alzheimers Dis 51:501–514, 2016 26890736
149 Reger MA, Watson GS, Green PS, Wilkinson CW, Baker LD, Cholerton B, Fishel MA, Plymate SR, Breitner JC, DeGroodt W, Mehta P, Craft S: Intranasal insulin improves cognition and modulates beta-amyloid in early AD. Neurology 70:440–448, 2008 17942819
150 DeFronzo RA: Pharmacologic therapy for type 2 diabetes mellitus. Ann Intern Med 133:73–74, 2000 10877745
151 Friedrich MJ: New research on Alzheimer treatments ventures beyond plaques and tangles. JAMA 308:2553–2555, 2012 23268496
152 Lane RF, Raines SM, Steele JW, Ehrlich ME, Lah JA, Small SA, Tanzi RE, Attie AD, Gandy S: Diabetes-associated SorCS1 regulates Alzheimer’s amyloid-beta metabolism: evidence for involvement of SorL1 and the retromer complex. J Neurosci 30:13110–13115, 2010 20881129
153 Leibson CL, Rocca WA, Hanson VA, Cha R, Kokmen E, O’Brien PC, Palumbo PJ: Risk of dementia among persons with diabetes mellitus: a population-based cohort study. Am J Epidemiol 145:301–308, 1997 9054233
154 Arvanitakis Z, Wilson RS, Bienias JL, Evans DA, Bennett DA: Diabetes mellitus and risk of Alzheimer disease and decline in cognitive function. Arch Neurol 61:661–666, 2004 15148141
155 Whitmer RA, Sidney S, Selby J, Johnston SC, Yaffe K: Midlife cardiovascular risk factors and risk of dementia in late life. Neurology 64:277–281, 2005 15668425
156 Cheng D, Noble J, Tang MX, Schupf N, Mayeux R, Luchsinger JA: Type 2 diabetes and late-onset Alzheimer’s disease. Dement Geriatr Cogn Disord 31:424–430, 2011 21757907