# CHAPTER 23 Peripheral and Autonomic Neuropathy in Diabetes

## Summary

Diabetes is the most common cause of neuropathy in the United States. Of hospital discharges between 2005 and 2010 among those age ≥18 years, 7.8% had an International Classification of Diseases, Ninth Revision (ICD-9), code of Diabetes with Neurological Manifestations, and 4.6% of discharges had a code of Polyneuropathy in Diabetes. This far exceeds hospital discharges coded for any other cause of neuropathy.

Classification systems have been developed for a number of manifestations of neuropathy. Among these various forms, the most common is distal symmetrical polyneuropathy (DSPN). The reported incidence and prevalence vary widely from study to study. These differences are likely attributable to several factors, including the population studied, the criteria used to diagnose DSPN, and the modalities used to detect the condition. Among type 1 diabetes patients, one prospective study found a 29% cumulative incidence after approximately 5 years of follow-up, while another found a cumulative incidence of 35% over a follow-up of 13–14 years.

DSPN is associated with several risk factors, of which glucose levels and the duration of diabetes appear to be the most influential. However, associations have been found with other characteristics, including height, blood pressure, and lipid levels.

Autonomic neuropathy is another troubling complication of diabetes. Of its multiple manifestations, cardiovascular autonomic neuropathy (CAN) has been the most studied. Similar to DSPN, incidence and prevalence estimates vary. In a large study of patients with type 1 diabetes who had normal autonomic function at baseline, less than 10% were found to have CAN after approximately 5 years of follow-up. CAN increases substantially with diabetes duration to rates as high as 35% after 22 years in individuals with type 1 diabetes and to 60% in patients with type 2 diabetes. Differences in prevalence and incidence estimates of CAN also could be attributable to differences in study populations, diagnostic criteria, and tests utilized for detection.

Risk factors have been identified for autonomic neuropathy. Although glycemia is a risk factor among individuals with type 1 diabetes, it has not clearly been identified as such for individuals with type 2 diabetes. Autonomic neuropathy has also been associated with cardiovascular risk factors.

In an analysis performed for Diabetes in America, 3rd edition, heart rate (beats/minute) was significantly higher in adults with diagnosed diabetes (mean 75.8) compared with those with normal glucose levels (mean 68.9). Heart rate was also higher in those who were diagnosed at the study visit with diabetes (mean 73.9) or prediabetes (mean 70.5) than in those with normal glucose levels. Of those with diabetes, the heart rate was significantly higher among diabetic individuals with glycosylated hemoglobin (A1c) ≥11.0% (mean 85.0) than among those with A1c <7.0% (mean 74.1). The basis for the higher heart rate among diabetic patients and the relation of heart rate to A1c are unknown. However, it is possible that heart rate, even within the normal range, is related to autonomic dysfunction.

A number of questions need to be answered with regard to diabetic neuropathy, such as whether glucose variability influences its development beyond the effects of the degree and duration of hyperglycemia. Such information should ultimately lead to a better understanding of how to treat and prevent the disorder.

## Introduction

Of all the long-term complications of diabetes, none affects as many organs or systems as the group of conditions that are included under the term “diabetic neuropathies.” The frequency with which diabetes affects the nervous system and the diverse manifestations of neuropathies might well explain the earlier view that diabetes was a consequence of, rather than a cause of, nerve dysfunction. Neuropathies have been described in patients with diabetes of differing causes, suggesting a common etiologic mechanism based on chronic hyperglycemia. The importance of hyperglycemia in the pathogenesis of neuropathy has received strong support from landmark studies, such as the Diabetes Control and Complications Trial (DCCT) (1,2,3). In the DCCT, the benefits of 6.5 years of intensive glucose control were maintained for at least 13–14 years after the end of the study (4,5).

The hallmark of the diabetic neuropathies is a progressive loss of all populations of nerve fibers, which can be assessed in a variety of ways. Although there are no major structural differences in nerve pathology between the two main types of diabetes, type 1 diabetes and type 2 diabetes, clinical differences do exist in the natural history and the prevalence of the various forms of neuropathy (6). The epidemiology and natural history of the neuropathies are not well defined, in large part due to variable diagnostic criteria and patient populations studied. The late sequelae of neuropathy are well recognized, with foot problems, including ulceration (7), gangrene, and Charcot neuroarthropathy (8), representing the most common cause of hospitalization among diabetic patients in most Western countries. Not surprisingly, diabetic neuropathy often has an adverse effect on quality of life (9,10,11).

## Definition of Diabetic Neuropathies

The consensus in the field is that diabetic neuropathies are defined by “the presence of symptoms and/or signs of peripheral and autonomic nerve dysfunction in people with diabetes after the exclusion of other causes” that are confirmed by a careful clinical examination (12). Absence of symptoms, however, cannot be equated with absence of neuropathy, as asymptomatic neuropathy is quite common (12,13,14,15). The exclusion of nondiabetic causes has also been emphasized, as up to 10% of peripheral neuropathy in diabetic patients may be of nondiabetic etiology (13,15,16). In addition, diabetic neuropathy should not be diagnosed on the basis of one symptom, sign, or test alone: a minimum of two abnormalities (from symptoms and signs) confirmed by nerve conduction abnormalities, quantitative sensory testing (QST), or quantitative autonomic tests is recommended (14,17,18).

## Classification of the Diabetic Neuropathies

Many classification systems for diabetic neuropathy have been proposed over the years based on their anatomical distribution (e.g., polyneuropathy or mononeuropathy, proximal or distal, symmetric or asymmetric, focal or multi-focal or diffuse), clinical course (e.g., acute, subacute, or chronic), or characteristic features (painful or non-painful, sensory, motor, or autonomic) (14,18,19,20,21). A new, simplified, yet comprehensive classification, based on the classifications proposed by the American Diabetes Association (ADA) (13), is now recommended for use in clinical practice (Table 23.1) (13,14,15).

The most typical form of diabetic neuropathy is a chronic, distal (length-dependent) symmetrical polyneuropathy (DSPN) that accounts for about 75% of cases (19). It is frequently associated with microvessel retinal and kidney disease, but other causes of neuropathy must be excluded (18).

Among these various forms of diabetic neuropathy, the most studied both in experimental and clinical trials are DSPN and cardiovascular autonomic neuropathy (CAN) (18,19,20,22,23). Therefore, findings presented in this chapter are mainly pertinent to these two forms of neuropathy.

### Distal Symmetrical Polyneuropathy

DSPN is the most common form of diabetic neuropathy, and most of the available evidence regarding the epidemiology, pathogenesis, and treatment is relevant to this form. It is usually of gradual onset and may be present at the diagnosis of type 2 diabetes in >10% of subjects (15,24). Up to 50% of patients may eventually develop symptoms and/or signs of DSPN (14,15). DSPN occurring in patients with abnormal glucose metabolism that is nonetheless insufficient to diagnose diabetes is sometimes classified as “impaired glucose tolerance” or “prediabetic” neuropathy (19).

The symptoms and sensory loss in DSPN associated with large and small fiber involvement are generally restricted to a “stocking distribution” (19). The “asleep or numb” sensation reflecting large fiber damage is not usually particularly painful, contrasting with the tingling, stabbing, and burning sensations that likely reflect small fiber involvement and ultimately result in persistent neuropathic pain affecting about 20% of diabetic patients (19,21,25). Late sequelae of DSPN include insensate foot ulceration, Charcot neuroarthropathy, and even amputation (15).

TABLE 23.1 Recommended Classification for Diabetic Neuropathies

Diabetic neuropathies
A. | Diffuse neuropathy
| Distal symmetrical polyneuropathy (DSPN)
| Primarily small fiber neuropathy
| Primarily large fiber neuropathy
| Mixed small and large fiber neuropathy (most common)
| Autonomic
| Cardiovascular
| Reduced heart rate variability
| Resting tachycardia
| Orthostatic hypotension
| Sudden death (malignant arrhythmia)
| Gastrointestinal
| Diabetic gastroparesis
| Diabetic enteropathy (diarrhea)
| Colonic hypomotility (constipation)
| Urogenital
| Diabetic cystopathy (neurogenic bladder)
| Erectile dysfunction
| Female sexual dysfunction
| Sudomotor dyfunction
| Distal hypohydrosis/anhidrosis
| Gustatory sweating
| Hypoglycemia unawareness
| Abnormal pupillary function
B. | Mononeuropathy (mononeuritis multiplex) (atypical forms)
| Isolated cranial or peripheral nerve (e.g., CN III, ulnar, median, femoral, peroneal)
| Mononeuritis multiplex (if confluent may resemble polyneuropathy)
C. | Radiculopathy or Polyradiculopathy (atypical forms)
| Radiculoplexus neuropathy (also known as: lumbosacral polyradiculopathy, proximal motor amyotrophy)
| Thoracic radiculopathy
Nondiabetic neuropathies common in diabetes
Pressure palsies
Chronic inflammatory demyelinating polyneuropathy
Acute painful small fiber neuropathies (treatment-induced)

SOURCE: Reference 15, copyright © 2017 American Diabetes Association, reprinted with permission from The American Diabetes Association

### Atypical Forms of Diabetic Neuropathy

#### Diabetic Radiculoplexus Neuropathy

Diabetic radiculoplexus neuropathy (DRPN), also called proximal motor neuropathy, most often presents with a lumbosacral distribution (also known as diabetic amyotrophy). It affects about 1% of diabetic patients who are typically middle aged or older and have type 2 diabetes (19). DRPN presents subacutely with girdle-like pain, usually very difficult to manage, followed by asymmetric proximal leg weakness and profound atrophy. It has a monophasic course, with improvement beginning within 9–12 months, although recovery can be incomplete and protracted over years (19).

#### Focal Peripheral Neuropathies

Focal peripheral neuropathies usually involve cranial, thoracic, or extremity nerves.

Focal limb neuropathies are often due to entrapment; the most susceptible nerves include the median, ulnar, radial, lateral femoral cutaneous, fibular, and plantar (19). Oculomotor palsy is the most common cranial neuropathy. It presents with acute onset of unilateral headache, ptosis, and impaired extraocular movements, but with a pupil that responds normally to light (19).

#### Acute Painful Small Fiber Neuropathies

Acute painful small fiber neuropathies (SFN) are characterized by the subacute onset of painful sensations in the legs, progressing over days to weeks to unremitting burning dysesthesias and allodynia. They are associated with minimal or absent sensory loss and preserved ankle reflexes. Since small nerve fiber involvement is not evaluated by conventional neurophysiological studies, its documentation requires additional testing, including measures of thermal thresholds, heart rate variation, sweat production, or skin biopsy (19). There are also forms of SFN associated with weight loss or treatment (19), including with rapid blood glucose lowering (26). The symptoms usually gradually improve with establishment of stable blood glucose levels (26).

#### Chronic Inflammatory Demyelinating Polyneuropathy

Chronic inflammatory demyelinating polyneuropathy (CIDP) is an immune-mediated neuropathy that has been suggested to occur more commonly in people with diabetes. However, its relationship to diabetes is controversial, since it could be a chance occurrence of two common disorders. An unmasking of mild diabetes among some CIDP patients treated with corticosteroids is possible (19). As CIDP may present clinically in a similar fashion to DRPN and often responds to immunotherapy, the differential diagnosis between these two conditions is very important.

### Diabetic Autonomic Neuropathy

Diabetic autonomic neuropathy (DAN) can involve a number of different systems, including cardiovascular, gastrointestinal, urogenital, and sudomotor. This might result in an array of symptoms and signs, such as postural hypotension, decreased bowel motility, decreased bladder contractility, erectile dysfunction, and sweating disorders. More advanced disease, manifested by debilitating symptoms and signs, is usually very difficult to treat and fortunately rare. Some of the various manifestations are described below. Symptoms of the various forms of DAN are listed in Table 23.2 (15). Among all forms of DAN, most available evidence from experimental and clinical studies regarding natural history, pathogenesis, and treatment is pertinent to CAN (15,19,27).

#### Cardiovascular Autonomic Neuropathy

The earliest sign of CAN is impaired heart rate variability (HRV), which may be completely asymptomatic (15,23,28,29). In more advanced cases, patients may present with resting tachycardia and exercise intolerance due to a reduced response in heart rate and blood pressure, as well as blunted increases in cardiac output with exercise (Table 23.2) (15,23,28,29).

TABLE 23.2 Symptoms Associated With Diabetic Autonomic Neuropathy

CARDIOVASCULAR AUTONOMIC NEUROPATHY | GASTROINTESTINAL AUTONOMIC NEUROPATHY | UROGENITAL AUTONOMIC NEUROPATHY
Resting tachycardia; Abnormal blood pressure regulation; ■ Non-dipping; ■ Reverse dipping; Exercise intolerance; Orthostatic hypotension; ■ Lightheadedness; ■ Weakness; ■ Faintness; ■ Dizziness; ■ Visual impairment; ■ Syncope; (all with standing) | Gastroparesis; ■ Nausea; ■ Bloating; ■ Loss of appetite; ■ Early satiety; ■ Postprandial vomiting; Esophageal dysfunction; ■ Heartburn; ■ Dysphagia for solids; Diabetic diarrhea; ■ Profuse and watery diarrhea; ■ Fecal incontinence; Constipation | Bladder dysfunction; ■ Frequency; ■ Urgency; ■ Nocturia; ■ Hesitancy; ■ Weak stream; ■ Dribbling; ■ Urinary incontinence; ■ Urinary retention; Male sexual dysfunction; ■ Erectile dysfunction; ■ Decreased libido; ■ Abnormal ejaculation; Female sexual dysfunction; ■ Decreased sexual desire; ■ Increased pain during intercourse; ■ Decreased sexual arousal; ■ Inadequate lubrication

SOURCE: Adapted from Reference 15, copyright © 2017 American Diabetes Association, reprinted with permission from The American Diabetes Association

Orthostatic hypotension (a fall in systolic or diastolic blood pressure in response to a postural change from supine to standing) occurs in diabetes largely as a consequence of efferent sympathetic vasomotor denervation, causing reduced vasoconstriction of the splanchnic and other peripheral vascular beds (23,28,29).

#### Gastrointestinal Autonomic Neuropathy

The effect of autonomic neuropathy on the gastrointestinal system can have several manifestations.

Esophageal dysfunction results, at least in part, from vagal dysfunction. Associated symptoms include heartburn and dysphagia for solids.

Gastroparesis is due to delayed gastric emptying and may manifest with a broad, but nonspecific, spectrum of symptoms and signs (Table 23.2) (30,31). The prevalence data on gastroparesis are limited, mainly because gastric emptying studies, necessary for proper diagnosis, may be difficult to perform in population studies.

From these limited data, idiopathic gastroparesis appears to be the most common category, followed by diabetic gastroparesis (32). Data from the Rochester Epidemiology Project, a database of linked medical records of residents of Olmsted County, Minnesota, showed that the age-adjusted incidence of definite gastroparesis per 100,000 person-years for 1996–2006 was 9.8 for women and 2.4 for men in the general population (33).

Regarding diabetic gastroparesis, most data are from selected case series rather than larger populations, and there is inconsistency in the outcome measure used (31) or in excluding other factors with direct effect on gastrointestinal motility (31). Earlier reports, that predated the routine use of intensive glucose management, described prevalence rates of up to 50% of patients with longstanding diabetes (30). More recently, in the only community-based study of gastroparesis in diabetes, the cumulative incidence of symptoms and delayed gastric emptying over 10 years was higher in type 1 diabetes (5%) than in type 2 diabetes (1%) and controls (1%) (34). However, there are several classes of medication (especially opioids, other pain management agents, glucagon-like peptide-1 [GLP-1] receptor agonists, pramlintide) and other factors that may considerably delay gastric emptying both in diabetic and nondiabetic patients. These factors should be considered before a diagnosis of diabetic gastroparesis is confirmed (30). Advanced cases dominated by severe nausea and postprandial vomiting can complicate diabetes control and reduce the quality of life (30).

Intestinal dysfunction may manifest as profuse and watery diarrhea sometimes alternating with constipation. This may be challenging to treat. Diabetic diarrhea is typically intermittent, occurring at night, and is more likely to occur in patients with other forms of autonomic dysfunction (30). The prevalence rates of a pure autonomic diabetic diarrhea are unclear, given that diarrhea may be associated with many other conditions that can coexist in diabetes, such as infectious causes, various drugs, and irritable bowel disease. People with diabetes may also experience fecal incontinence due to poor sphincter tone.

#### Urogenital Autonomic Neuropathy

Bladder dysfunction may occur in up to 50% of people with diabetes (30). Symptoms are diverse and include frequency, urgency, nocturia, hesitancy, a weak stream, dribbling and urinary incontinence, and urinary retention (Table 23.2).

Erectile dysfunction is present in 30%–75% of diabetic men (30). It has a multifactorial etiology that includes autonomic neuropathy, other vascular risk factors (hypertension, hyperlipidemia, obesity, endothelial dysfunction, smoking, and cardiovascular disease), concomitant medication, and psychogenic factors.

Female sexual dysfunction may occur in diabetic women and present as decreased sexual desire, increased pain during intercourse, decreased sexual arousal, and inadequate lubrication.

#### Other Manifestations of Autonomic Neuropathy

Autonomic neuropathy can lead to sudomotor dysfunction with such manifestations as anhidrosis, heat intolerance, dry skin, and hyperhidrosis (35). An unawareness of hypoglycemia could also possibly be related to autonomic neuropathy.

## Assessment of Diabetic Neuropathies

This section focuses on assessments of DSPN and CAN, which have been most studied in epidemiologic and randomized clinical studies (27). For details on the other forms of diabetic neuropathy, readers are referred to detailed texts (19,21,36).

### Distal Symmetrical Polyneuropathy

The diagnosis and staging of DSPN are important not only for day-to-day clinical practice but also for research assessing etiology, natural history, pathogenesis, and new treatments. The Peripheral Nerve Society issued a Consensus Statement on measures to assess efficacy in controlled trials of new therapies for neuropathy in 1995 (37), and more recently, in 2009, the Toronto Consensus on Diabetic Neuropathies panel reviewed the definitions and diagnostic criteria of DSPN for possible, probable, confirmed, and subclinical categories (18).

The Toronto panel defined possible DSPN as appropriate sensory symptoms OR signs (symmetrical decrease in distal sensation or unequivocally abnormal ankle reflexes). Probable DSPN was defined as at least two abnormalities among sensory symptoms, sensory signs, or ankle reflexes. Confirmed DSPN was defined as symptoms OR signs (sensory or ankle reflexes) AND an abnormal nerve conduction study, whereas subclinical DSPN was defined as an abnormal nerve conduction study, without signs or symptoms (18,19).

In clinical practice, DSPN remains a clinical diagnosis, and equipment requiring an electrical power source or referral to a neurologist is not usually needed in the assessment of peripheral nerve function (13,24), except in situations where the clinical features are atypical, the diagnosis is unclear, and a different etiology is suspected (14,22).

#### Symptoms

The accurate recording of symptoms is a basic element of the assessment of neuropathy. A number of simplified composite scores of symptoms have been developed, such as the Neuropathy Symptom Score (NSS), the Neuropathy Symptom Profile (NSP) (24), and the symptoms questionnaire of the Michigan Neuropathy Screening Instrument (MNSI). The MNSI comprises a 15-item, yes/no symptom questionnaire that is supplemented by a simple clinical exam. The simplified NSS and the MNSI have been used for epidemiologic studies (24,38,39) and can be easily applied in clinical practice for diagnosis or patient follow-up, as they are easy to administer. The McGill Pain Questionnaire, which is a general pain instrument, also has been used by several research groups.

In addition, the quality of life has increasingly been emphasized as an important factor in the natural history of neuropathic symptomatology, and specific instruments have been developed and validated for use in diabetic neuropathy, such as the NeuroQoL (40), the MNSI (41), and the Norfolk QOL-DN (42).

#### Clinical Signs

Simple clinical observation of the feet and legs after the removal of shoes and socks may identify a neuropathic foot: evidence might include small muscle wasting, clawing of the toes, prominent metatarsal heads, dry skin and callus (secondary to sympathetic autonomic dysfunction), and occasionally the typical foot deformity secondary to Charcot neuroarthropathy.

Two simple instruments can be used in clinical practice or for clinical trial assessment. First, the clinical examination part of the MNSI, which includes foot examination, the assessment of ankle reflexes, and the measurement of vibration perception at the great toe (see the Quantitative Sensory Testing section) (41), is a sensitive and specific instrument for diagnosis of DSPN (38,41). It has been used in major large clinical trials, including the DCCT/Epidemiology of Diabetes Interventions and Complications study (EDIC) (38,39), the Action to Control Cardiovascular Risk in Diabetes (ACCORD), and the Bypass Angioplasty Revascularization Investigation 2 Diabetes (BARI 2D) (27,43). Second, the simplified neuropathy disability score (NDS) requires a simple clinical examination that sums abnormalities of reflexes and sensory assessments. It has been used in clinical practice and in epidemiologic studies (24,44).

#### Quantitative Sensory Testing

QST assesses the patient’s ability to detect a variety of sensory stimuli that characterize both large and smaller nerve fibers. This methodology also has a large degree of subjectivity, as results are a function of the patient’s concentration and cooperation. Moreover, an abnormal finding does not necessarily indicate peripheral neuropathy; the abnormality may lie anywhere in the afferent neural pathway. QST methods vary in complexity: the simpler instruments can be used in day-to-day clinical practice, whereas the more sophisticated instruments, usually requiring more expensive equipment and an external power source, are commonly used for more detailed assessment and for follow-up assessments in clinical trials. Some of the more commonly used techniques are now briefly described.

Semmes-Weinstein monofilaments comprise sets of nylon filaments of variable diameter that buckle at a predefined force when applied to the testing site—usually the dorsal aspect of the halluces at the metatarsal-phalangeal joints area and plantar surfaces. They are widely used in clinical practice and are particularly helpful in identifying individuals who are at risk of neuropathic foot ulceration. The inability to perceive pressure of 10 g (5.07) monofilaments has been shown in prospective studies to be indicative of higher risk for neuropathic ulceration (45).

Vibration perception, indicative of myelinated fiber function, can be assessed with several devices. The vibration perception threshold increases with age in nondiabetic individuals and tends to be higher in the lower extremities. As well as being useful in clinical practice, the vibration perception threshold has been used in clinical research and epidemiologic studies (19,27). A simple pocket-sized disposable device, the Vibratrip, has been validated as a useful tool in the clinical setting and may also be useful for the prediction of patients at risk for foot ulceration in the research setting (46).

Thermal and cooling thresholds are also used to assess sensory function. Warm and cold sensations are transmitted by small myelinated and unmyelinated fibers and can be assessed with several devices. Since these tend to be expensive, they are used mostly for clinical research and for detailed clinical assessment (24).

Computer assisted sensory examination (CASE) is a complex methodology that is regarded as the state of the art for clinical trials. It is a computerized device that can measure touch, pressure, vibration, and warm/cold thresholds using a forced-choice algorithm. CASE is not typically used in day-to-day clinical practice (18).

#### Electrophysiology

Electrophysiological tests are objective, noninvasive, and highly reliable measures that do not depend on a patient’s response. However, these tests only measure large fiber afferent and motor nerve function and, therefore, are of limited use in the evaluation of small-fiber deficits (47,48,49). The 2009 Toronto Consensus Panel concluded that composite sum scores based on deviations (from percentiles) of nerve conduction study attributes (e.g., fibular and tibial conduction velocity, sural amplitude) performed best among these tests for diagnosing DSPN (18). More easily applied criteria (e.g., use of ≥1 abnormal attribute in two separate lower extremity nerves based on 1st and 99th percentile values) perform well (19).

Composite scores that combine electrophysiological measures with clinical, quantitative, and sensory assessments are often used in research studies evaluating the natural history of DSPN or the efficacy of various interventions (14,18). However, electrophysiological testing or referral to a neurologist is rarely needed for diagnosis of DSPN in clinical practice, except in situations where the clinical features are atypical, the diagnosis is unclear, or a different etiology is suspected, as recommended in the ADA Statement on Diabetic Neuropathy based on most recent evidence (15).

#### Skin Biopsy and Corneal Confocal Microscopy

Immunohistochemical quantification of intra-epidermal nerve fiber density (IENFD) using punch skin biopsies has increasingly been used to quantify small fiber neuropathies in diabetes (50). The introduction of corneal confocal microscopy (CCM) represents a novel reiterative in vivo clinical examination technique that is capable of imaging corneal nerve fibers in a noninvasive technique (51). CCM has the capacity to detect early nerve fiber repair 6 months after restoration of euglycemia following pancreas transplantation in type 1 diabetes patients (52).

### Cardiovascular Autonomic Neuropathy

Several diagnostic approaches with varying degrees of complexity are available to diagnose CAN in practice or research, including the assessment of cardiovascular reflex testing, HRV, 24-hour blood pressure profiles, orthostatic hypotension, baroreflex sensitivity, cardiac sympathetic imaging, microneurography, or occlusion plethysmography.

#### Assessment of Symptoms

Symptoms associated with CAN include exercise intolerance, orthostatic intolerance, and syncope (Table 23.2) (15,53). The correlation between symptom scores and deficits is generally weak in mild CAN, as these symptoms usually occur late in the disease process. Using a validated self-report measure of autonomic symptoms in a population-based study, Low et al. found that autonomic symptoms were present more commonly in type 1 diabetes than in type 2 diabetes (53).

#### Cardiovascular Autonomic Reflex Tests

Based on the strongest lines of evidence available to date, cardiovascular autonomic reflex tests (CARTs) are the most sensitive, specific, reproducible, safe, and standardized measures (15,23,28,29,35,54). Therefore, their use is recommended as the gold standard for clinical autonomic testing (15,28).

These tests, first described in the 1970s (55,56), assess cardiovascular autonomic function using provocative physiological maneuvers and include: (1) changes in R-R interval from an electrocardiogram (ECG) with deep breathing, a measure of sinus arrhythmia during quiet respiration reflecting primarily parasympathetic function (35); (2) the R-R response to standing, inducing reflex tachycardia followed by bradycardia, which is jointly vagal- and baroreflex-mediated; (3) the Valsalva ratio, which evaluates cardiovagal function in response to a standardized increase in intrathoracic pressure (Valsalva maneuver); and (4) orthostatic hypotension (28). Although no test is clearly superior (28), the deep breathing test is the most widely used due to its high reproducibility, approximately 80% specificity (57), and ease of use (28,35,57). The Valsalva maneuver requires greater patient cooperation. Due to the associated increase in intrathoracic, intraocular, and intracranial pressure, it could theoretically result in intraocular hemorrhage or lens dislocation; thus, it cannot be universally performed (28), although there is no clear evidence regarding the extent of this risk. Test abnormalities should be defined using age-specific normative data (28). Detailed descriptions of CART standardization, analysis, and staging are provided elsewhere (28,58).

#### Heart Rate Variability

In normal individuals, beat-to-beat variability with respiration, increasing with inspiration and decreasing with expiration, is due to the direct influence of sympathetic and parasympathetic stimuli. A decrease in HRV is the earliest clinical indicator of CAN (23,58,59). HRV can be evaluated in the time and frequency domain, derived from ECG recordings, ideally under paced breathing. Longer ECG recordings (e.g., 24-hour) were initially used exclusively, but shorter recordings also provide reliable information on cardiovascular autonomic function (23,58,60).

Time domain measures of the normal R-R intervals, basically reflecting parasympathetic activity, include: the difference between the longest and shortest R-R interval, standard deviation of 5-minute average of normal R-R intervals (SDANN), and root-mean square of the difference of successive R-R intervals (rMSSD) (60).

The frequency domain measures are obtained by spectral analysis of R-R interval and other respiratory and cardiovascular signals (58). It is traditionally accepted that the parasympathetic system affects the high frequency components (0.15–0.4 Hz), the sympathetic activity essentially influences a rather narrow band around 0.1 Hz (low frequency), and the very low frequency components (<0.04 Hz) are essentially related to fluctuations in vasomotor tone associated with thermoregulation or activity (58). A variety of mathematical methods used to analyze HRV and the commercially available software programs for assessment of HRV are broadly covered in Bernardi et al. (58). It is generally recommended that HRV testing be used for research and in conjunction with CART (58). The accuracy of all HRV measures is affected by various arrhythmias, and the analysis requires normal sinus rhythm and atrioventricular-nodal function.

## Pathogenesis of the Diabetic Neuropathies

The specific mechanisms contributing to diabetic DSPN are not completely understood. It is generally accepted that the pathogenesis of diabetic DSPN is multifactorial, involving complex interactions between the degree of glycemic control, diabetes duration, age-related neuronal attrition, and other factors, such as blood pressure, lipid levels, and weight (19). These promote progressive peripheral and autonomic neural dysfunction in a fashion that begins distally and progresses proximally. Hyperglycemia plays a key role in the activation of various biochemical pathways related to the metabolic and/or redox state of the cell, which in concert with impaired nerve perfusion contribute to the development and progression of diabetic neuropathies.

Experimental data implicate a number of pathogenic pathways that may impact the peripheral and autonomic neuronal function in diabetes, including: increased mitochondrial production of free radicals and increased oxidative/nitrosative stress, formation of advanced glycation endproducts, downregulation of the soluble receptor for advanced glycation endproducts (sRAGE), activation of the polyol and protein kinase C pathways, activation of polyADP ribosylation, and activation of genes involved in neuronal damage, cyclooxygenase-2 activation, endothelial dysfunction, altered function of the Na+/K+-ATPase pump, impaired C-peptide-related signaling pathways, endoplasmic reticulum (ER) stress with resulting accumulation of unfolded or misfolded proteins within the ER lumen, and activation of several apoptotic processes (19,23,59,61,62,63,64,65).

Low-grade inflammatory processes may also play an important role in the pathogenesis of diabetic neuropathies. Some could be mediated by NF-kappaB activation and downstream effects (66,67) with deficits in peripheral and autonomic nerve fibers (59,66,68). Altered mitochondrial bioenergetics in dorsal root ganglia neurons appear to be modulated by the heat shock protein (Hsp) 70. Ciliary neurotrophic factors also could be important (19,69,70).

Emerging data in human studies suggest that peripheral nerve dysfunction and changes in the sympathetic and parasympathetic system function may occur prior to the development of diabetic range hyperglycemia in individuals with features of the metabolic syndrome or in patients with impaired glucose tolerance (71,72). These changes appear to correlate with an increase in adipose tissue-derived inflammatory markers (73,74). A detailed review of these mechanisms and their complex interactions is beyond the scope of this chapter.

## Treatment

In line with the evidence discussed above, this section provides a general overview of treatments for DSPN and CAN. For more detailed information and for other forms, readers are referred to detailed texts (19,21).

There is a distinction between therapies that might alter (slow) the progressive loss of nerve fiber function that characterizes the natural history of neuropathy (disease-modifying therapies) and those for symptomatic relief (75). Some interventions have efficacy in both areas.

### Disease-Modifying Treatments

Of disease-modifying therapies, tight and stable glycemic control, implemented early in the course of diabetes, is most supported by data to delay development of DSPN and CAN in patients with type 1 diabetes (1,2,3,27,76,77) and to promote long-time protection, especially for CAN (4,5,27,78).

The effects of glycemic control on DSPN or CAN are less conclusive for type 2 diabetes (27). Data from the 1990s suggested that glucose control was beneficial if implemented earlier in the disease course in patients with fewer comorbidities (79). ACCORD, the largest type 2 diabetes trial, reported a significant DSPN risk reduction in the intensive glycemia strategy arm after 5 years of follow-up (80), although other large studies did not confirm these findings (81,82,83,84). Some studies have suggested that rapid improvement in blood glucose may induce symptoms and signs of neuropathy, especially neuropathic pain (26).

Emerging data suggest that, in type 2 diabetes, the strategies used to reach glycemic goals may be as important as the glucose control achieved (27). The BARI 2D trial reported that specific glucose-lowering strategies and medications used to reach glycemic goals also have different effects in preventing DSPN in type 2 diabetes (85).

Lifestyle interventions, particularly diet and exercise consisting of moderately intense aerobic and resistance training, improve neuropathic symptoms and IENFD among patients with DSPN associated with impaired glucose tolerance and with diabetes (86,87).

An intensive multifactorial cardiovascular risk factor intervention targeting glucose, blood pressure, lipids, smoking, and other lifestyle factors reduced the progression or the development of CAN among type 2 diabetes patients (88). Data regarding the impact of lifestyle interventions in preventing progression of CAN are emerging (71). In the Diabetes Prevention Program, indices of CAN improved more in the lifestyle modification arm than in the metformin or placebo arms (Figure 23.1) (71). Some smaller trials reported that the combination of strictly supervised endurance training and dietary changes was associated with improved HRV in overweight patients who had minimal abnormalities (29). This outcome was possibly mediated by the effects of weight loss on cardiovascular autonomic function (89).

Earlier trials of potential disease-modifying therapies, including aldose-reductase inhibitors, various antioxidants, recombinant nerve growth factors, and acetyl-carnitine, did not show appreciable benefit (61,90,91). Other therapies, such as alpha-lipoic acid (92,93,94), C-peptide (95,96), actovegin (97), and a combination of L-methylfolate, methylcobalamin, and pyridoxal-5’-phosphate (98), have shown some promise on symptomatic relief for DSPN, but the evidence from multicenter randomized clinical trials on objective measures of DSPN is very limited, with most being largely negative as disease-modifying treatments. Most recently, a phase IIb clinical trial evaluating the efficacy and safety of long-acting synthetic C-peptide in patients with type 1 diabetes and mild DSPN reported no difference in nerve conduction studies and clinical outcomes of DSPN compared with placebo (99).

FIGURE 23.1 Indices of Cardiovascular Autonomic Neuropathy Are Improved by Lifestyle Modification, Diabetes Prevention Program

Changes in heart rate, heart rate variability indexes, and QT duration over time by treatment arm. QTc, Bazett’s correction; rMSSD, root mean square of successive differences between all normal-to-normal R-R intervals; SDNN, standard deviation of all normal-to-normal R-R intervals.

* p<0.05, placebo versus lifestyle

† p<0.05, placebo versus metformin

‡ p<0.05, metformin versus lifestyle

Line graphs showing that indices of cardiovascular autonomic neuropathy improved more in the lifestyle modification arm compared to metformin or placebo arms.

SOURCE: Reference 71, copyright © 2006 American Diabetes Association, reprinted with permission from The American Diabetes Association

Regarding CAN, few phase II randomized controlled trials have shown favorable effects on HRV indices using the antioxidant alpha-lipoic acid, vitamin E, or C-peptide (23,28). Larger studies are needed to confirm these findings, as well as to evaluate new, effective potential pathogenetic treatments.

### Symptomatic Treatment

Whereas a number of treatments are available for painful symptomatic DSPN, there are no specific therapies for patients with painless neuropathy or for other symptoms. However, as stated below, all of these patients warrant foot care education and regular podiatric care (45).

Neuropathic pain can affect several aspects of a patient’s life, so a multidisciplinary approach is essential in managing the condition. In many cases, the clinical assessment indicates the need for psychological or physical therapy in addition to standard pharmacologic treatments. Support and information on practical measures, such as using a bed cradle to lift the bed clothes off hyperesthetic skin, often prove invaluable. Pharmacologic agents include anticonvulsants, serotonin and norepinephrine reuptake inhibitors, tricyclic antidepressants, topical and physical treatments. The ADA Statement on Diabetic Neuropathy summarized the available evidence on the most effective agents for treating neuropathic pain in diabetes, including U.S. Food and Drug Administration-approved drugs and other agents that should be considered in clinical decision making (15). Given the high risk of addiction, abuse, sedation, and other complications and psychosocial issues even with short-term opioid use, opioids are not recommended in the treatment of painful DSPN before failure of other agents (15) that do not have these associated concerns.

As indicated above, a number of troubling symptoms can occur from manifestations of CAN or other forms of DAN, including orthostatic hypotension, gastroparesis, diabetic diarrhea, erectile dysfunction, and bladder dysfunction. There is no overall treatment for these entities; each treatment must be individualized.

## Epidemiology and Natural History of Distal Symmetrical Polyneuropathy and Cardiovascular Autonomic Neuropathy

Diabetes is by far the most common cause of neuropathy in the United States. The National Hospital Discharge Survey provides strong evidence for this. In a new analysis for Diabetes in America, 3rd edition, data from hospital discharges between 2005 and 2010 among those age ≥18 years, showed that 7.8% of discharges had an International Classification of Diseases, Ninth Revision (ICD-9), code of Diabetes with Neurological Manifestations, and 4.6% of discharges had a code of Polyneuropathy in Diabetes (data not shown). In comparison, the percentage of discharges with a code for Alcoholic Polyneuropathy, Polyneuropathy due to Drugs, or Polyneuropathy due to Other Toxic Agents was extremely low (<0.001% for Alcoholic Polyneuropathy; number of discharges for Polyneuropathy due to Drugs or Polyneuropathy due to Other Toxic Agents was too small for a valid estimate).

Since there are a number of methods by which the presence and degree of severity of diabetic neuropathy are assessed, studies of the natural history and epidemiology of diabetic neuropathy should be examined with attention to the specific assessments and criteria for neuropathy that were used. Other factors also should be considered, such as characteristics of the study population, the type of diabetes, and study design.

Although a great deal of natural history and epidemiologic information has been obtained from studies performed in the United States, valuable information has also been obtained from studies in other locales. Thus, findings from those other studies are included in this discussion. As mentioned, the vast majority of studies have examined the natural history and epidemiology of DSPN and CAN. Thus, these forms are the focus of this section.

### Distal Symmetrical Polyneuropathy

#### Incidence and Prevalence

Incidence estimates of DSPN among type 1 diabetes patients have been examined in several large studies. In the observational follow-up of the DCCT cohort, the EDIC study, 25% and 35%, respectively, of the former intensive and conventional treatment groups had confirmed clinical neuropathy at year 13–14 (4). In the Wisconsin Epidemiologic Study of Diabetic Retinopathy (WESDR) (76), depending on characteristics of the type 1 diabetes patients who were studied, there was decreased tactile sensation in 19%–25% and decreased temperature sensitivity in 11%–19% after 10 years of follow-up. In the Pittsburgh Epidemiology of Diabetes Complications Study (EDC), in which patients with type 1 diabetes were followed, the cumulative incidence of DSPN over a period of 5.3 years was 29% (77).

The importance of methodology in considering epidemiologic findings is particularly evident in studies of type 2 diabetes patients, such as the San Luis Valley Study. In that study, the incidence of DSPN without a confirmatory examination was approximately 5 per 100 person-years, whereas the incidence was <1 per 100 person-years when a confirmatory examination was performed (100). The prevalence of vibratory perception abnormalities in adult patients is highly dependent on the site of measurement. The more distal the measurement, the higher the prevalence, even from the lateral malleolus to the hallux (101).

Temporal trends can be an important consideration in assessing the incidence of DSPN. Data from the EDC revealed a decline in the incidence of DSPN over a period of years (102). Among those with a 25-year duration of type 1 diabetes, the cumulative incidence for those diagnosed between 1970 and 1974 was significantly lower than among those diagnosed between 1965 and 1969.

The prevalences of the various manifestations of DSPN have varied widely. In the National Health Interview Survey 1989 of an adult population, the prevalence of pain and/or tingling among those with diabetes was 27% (6). However, an appreciable proportion of those without diabetes also had those symptoms; the prevalence was approximately 5%–10%. Thus, the difference between these estimates could be a better indication of the prevalence of painful neuropathy attributable to diabetes. In other studies, estimates of the prevalence of painful symptoms have ranged from 3% to >20% (7,13,16,103). Marked differences in the prevalence of hypoesthesia have been observed according to the mode of QST assessment. In one study, the prevalence varied between 8% and 34% according to the specific sensory test (104). Studies using combined assessments of neuropathy have also shown marked differences in the prevalence of DSPN. In one such study, the EURODIAB IDDM Complications Study (105), the prevalence ranged from <20% to >50% among the participating sites.

Ethnicity can be a major determinant of prevalence. Even within the American Indian population of the Strong Heart Study (106), there was marked variation; the percentage of those with at least 5 (of 10) incorrect monofilament responses was 22% in Arizona and only 8% in Oklahoma.

Studies have examined hearing loss in diabetic individuals, which could possibly be related to neuropathy. The National Health and Nutrition Examination Surveys (NHANES) 1999–2004 (107) revealed that low to middle frequency and high frequency hearing deficits were more common (21% and 54%, respectively) in diabetic patients. However, such hearing deficits were also appreciable in the nondiabetic population (9% for low/mid frequency and 32% for high frequency). This should be considered in estimating the actual prevalence of hearing loss attributable to diabetes.

Comparisons of DSPN prevalence between individuals with type 1 diabetes or type 2 diabetes are clouded by age differences. In the SEARCH for Diabetes in Youth Study (108), the prevalence of DSPN was higher in those with type 2 diabetes than in those with type 1 diabetes (17.7% vs. 8.5%, p<0.001). However, despite the young study population, those with type 2 diabetes were still older. After adjustments for established risk factors measured over time, youth with type 2 diabetes had significantly higher odds of DSPN versus youth with type 1 diabetes (adjusted odds ratio 2.52, 95% confidence interval [CI] 1.43–4.43, p=0.001) (108). In a cross-sectional multicenter study that included 6,487 randomly selected patients with type 1 diabetes and type 2 diabetes, the prevalence was 22.7% (95% CI 21.0%–24.4%) in type 1 diabetes and 32.1% (95% CI 30.6%–33.6%) in type 2 diabetes. However, the overall prevalence of DSPN increased with age, from 5% (95% CI 3.1%–6.9%) in the 20–29 years age group to 44.2% (95% CI 41.1%–47.3%) in the 70–79 years age group (109).

TABLE 23.3 Prevalence of Distal Symmetrical Polyneuropathy in Observational Studies Performed in the United States

STUDY, YEARS (REF.) | TYPE OF DIABETES (N)^*^ | RACE/ETHNICITY | AGE (YEARS) | ASSESSMENT(S) | PREVALENCE
Epidemiology of Diabetes Complications (EDC) Study, 1981 (77) | Type 1 (363) | Diverse | ≥18 | Clinical | 18–29 years: 18%; ≥30 years: 58%
Epidemiology of Diabetes Interventions and Complications (EDIC), 2006–2008 (4,78) | Type 1 (1,186) | White | 47±7 | Clinical + electrophysiology | 25% vs. 35% (former intensive vs. former conventional Diabetes Control and Complications Trial treatment groups)
SEARCH for Diabetes in Youth Study, 2011–2015 (108) | Type 1 (329); Type 2 (70) | Diverse | Type 1: 17.9±4.1^†^; Type 2: 22.1±3.5 | Clinical | Type 1: 8.5%; Type 2: 17.7%
National Health Interview Survey, 1989 (6) | Type 1 (124); Type 2 (2,268) | Diverse | ≥18 | Pain | 27%
Strong Heart Study, 1993–1995 (106) | Type 2 (2,051) | American Indian | 45–74 | Monofilament | 8%–22%; (depending on study site)
Seattle Prospective Diabetic Foot Study, 1988 (125) | Type 2 (778) | 78% white (veterans) | 63.2^‡^ | Monofilament | 50%

* If reported as IDDM, indicated as type 1 in the table; if reported as NIDDM, indicated as type 2 in the table.

† Mean±standard deviation

‡ Mean value calculated from available data

SOURCE: References are listed within the table.

Table 23.3 provides a summary of the prevalence of neuropathy found in observational studies performed in the United States. The wide variation in prevalence is evident. As indicated, this could well be attributable to variation in age, ethnicity, and type of diabetes. The table shows why it is important to specify these factors, and others, in assessing the prevalence of DSPN.

#### Natural History

The onset and course of DSPN are still not fully clear. It is possible that the pathologic process of DSPN may begin even before the onset of diabetes. Neuropathic changes in small nerve fibers are common in individuals with impaired glucose tolerance (110), a frequent precursor of both type 1 diabetes and type 2 diabetes. Also, clinical evidence of neuropathy has been reported in individuals with impaired glucose tolerance (72,111,112). Moreover, in the NHANES 1999–2004 (113), prediabetic and undiagnosed (i.e., diagnosed with diabetes at the NHANES visit) individuals age ≥40 years tended to have more areas of the foot insensate to 10 g monofilament stimulation than individuals with normal glucose values. Other factors besides glucose could play a role in those individuals, such as the presence of vascular disease.

Abnormalities in some neuropathy measurements have been observed relatively early in the course of both type 1 diabetes and type 2 diabetes. Vibration thresholds were found to be higher in children and adolescents with type 1 diabetes than those who were nondiabetic (114). In another study of type 1 diabetes patients, thermal thresholds increased more than vibration thresholds among those followed 5 years after diagnosis (115). Among individuals newly diagnosed with type 2 diabetes, decreases in vibration and thermal sensitivities were observed after 2 years of follow-up (116). In the United Kingdom Prospective Diabetes Study (UKPDS), 13% of patients at the diagnosis of type 2 diabetes had neuropathy of sufficient severity to put them at risk of foot ulceration attributable to insensitivity (83). However, in a study of type 2 diabetes patients that utilized the 10 g monofilament, the development of insensitivity was not marked in the years following diagnosis (106).

TABLE 23.4 Prevalence of ≥1 Monofilament Errors Among Adults Age ≥40 Years With Diagnosed Diabetes, by A1c Value, U.S., 1999–2004

PERCENT (STANDARD ERROR)
Diagnosed Diabetes, A1c | | | | Normal Glucose Levels
<7.0% | ≥7.0%–<9.0% | ≥9.0%–<11.0% | ≥11.0% | Normal Glucose Levels
23.6 (2.52)^*^ | 30.7 (2.63)^*^ | 32.3 (6.40)^*^ | 36.7 (9.08)^†^ | 8.5 (0.85)

Monofilament errors are the number of insensate areas on both feet (range 0–6). Diagnosed diabetes is based on self-report. Normal glucose is based on fasting plasma glucose <100 mg/dL and A1c <5.7%. Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin.

* p<0.001 compared to persons with normal glucose levels

† p<0.01

SOURCE: National Health and Nutrition Examination Surveys 1999–2004

DSPN usually persists once it occurs. This is especially evident from such measures as QST and nerve conduction. Although pain from neuropathy can eventually remit, this is not necessarily attributable to improvement in neuropathy. In one study (117), a slight improvement in electrophysiological testing with pain remission was evident. Patients with pain remission tended to develop their symptoms after a metabolic change, weight loss, or a short duration of diabetes. In a clinical trial of Japanese patients with type 2 diabetes (79), intensive insulin treatment with multiple insulin injections was associated with an improvement of DSPN. This was mainly based on improvement in nerve conduction studies. There is some evidence that the rate of progression becomes more rapid after decreased sensation is first evident (118,119). This has been observed both with regard to vibration and thermal thresholds.

#### Risk Factors

Among studies of type 1 diabetes patients, the DCCT (1,2,4) has provided the most definitive information of the association between DSPN and the degree of glycemia. During the DCCT, the prevalence of confirmed DSPN (defined as at least two positive findings among sensory symptoms, signs, or reflex abnormalities, and abnormal nerve conduction studies in two or more nerves among the median, peroneal, and sural nerves) increased slightly after an average follow-up of 6.5 years among the intensive treatment group participants (from 7% to 9%), but substantially more in the conventional treatment subjects (from 5% to 17%) (1). Adjusting for the presence of confirmed DSPN at baseline in the DCCT, the risk reduction for incident neuropathy with intensive treatment was 64% (95% CI 45%–76%) (1,2,78). Observational studies have also shown associations between the occurrence of DSPN and glucose levels (76,105). In the WESDR of type 1 diabetes patients, it was estimated that a 2% decrease in glycosylated hemoglobin (A1c) values over 4 years would be associated with a 9%–23% decrease (depending upon the study group) in the 10-year incidence of the loss of tactile sensation (76). In the EURODIAB study, the prevalence of DSPN increased with increasing A1c values (120).

Data from clinical trials of type 2 diabetes patients have mostly supported the association between DSPN and the degree of glycemia (27). In the UKPDS (83), a large trial designed to assess the impact of glucose control in type 2 diabetes patients, the incidence of a decline in vibratory sensation was lower in the intensive treatment group than in the conventional treatment group after 15 years of follow-up. However, differences between the groups were marginal when the intervals of follow-up were shorter. As mentioned, in the clinical trial of Japanese type 2 diabetes patients (79), those on more insulin injections had better neurologic outcomes. Although the ACCORD trial of type 2 diabetes patients was terminated early, intensive glucose control was associated with a reduction in the prevalence of several DSPN measures after 5 years of follow-up (80). However, in the Veteran Affairs Diabetes Trial (VADT) of type 2 diabetes patients, despite appreciable A1c differences between the intervention and control groups, there was little difference in the occurrence of DSPN (121). It should be noted that the VADT relied heavily on self-reporting, and DSPN was not a primary outcome measure (27).

Data from the NHANES 1999–2004 were analyzed for Diabetes in America to examine the relation between sensory impairment (as indicated by ≥1 areas in the foot insensate to a 10 g monofilament) and A1c among individuals age ≥40 years with diabetes. Table 23.4 shows the percentages with ≥1 incorrect responses to monofilament stimulation according to A1c categories among those with diagnosed diabetes. The percentage tended to increase with increasing A1c levels (from 23.6% for A1c <7.0% [<53 mmol/mol] to 36.7% for A1c ≥11.0% [≥97 mmol/mol]). Those in the A1c <7.0% category had a substantially higher percentage of monofilament scores ≥1 than did those with normal glucose levels (23.6% vs. 8.5%, p<0.001).

Despite evidence that DSPN is associated with the degree of glycemia, there is much more to be learned about the nature of that relationship. For instance, it has been postulated that higher glucose levels for even a limited period could have a marked impact on the risk of DSPN. Follow-up data from the EDIC study of former DCCT subjects have been utilized to assess whether there is a “metabolic memory” effect for DSPN. When DCCT participants were followed after the trial’s completion, DSPN continued to be more common in the conventional treatment group several years later, in spite of a narrowing in the A1c levels between the groups, which were no longer different starting at EDIC year 5 (39). Since the neurologic assessments for that study were less extensive than they were in the DCCT, a subsequent EDIC study of former DCCT participants was performed with the entire battery of DCCT assessments (4,122). Although there was a significant difference in the raw incidence, with an adjustment for neurologic status at the end of the DCCT, there was no longer evidence of a metabolic memory effect on the primary DSPN endpoint. However, the difference persisted for nerve conduction studies (4,78).

Glucose variability has been assessed as a risk factor for DSPN. In studies that have examined the possible impact of such variability, findings have been inconsistent (123,124).

Constitutional factors can influence the risk of DSPN. Height is a risk factor (101,103,106,125), with an increasing effect the more distal the assessment (101). The basis for this is not known, but it is possible that height is a surrogate for nerve length; longer nerves could be more susceptible to pathologic factors. Neurologic function declines with age in both diabetic and nondiabetic populations (126). Moreover, associations of DSPN with other risk factors can vary with age (77). Studies have shown associations between DSPN and genetic factors in both type 1 diabetes and type 2 diabetes patients (127,128).

Some studies have shown associations of DSPN with blood pressure and lipid measures (120), possible surrogates of vascular disease. Findings of studies examining associations of DSPN with alcohol consumption (101,106,125) and cigarette smoking (101,106,125,129) have been inconsistent.

Information regarding risk factors for diabetic hearing loss is limited. In the NHANES 1999–2004 (130), hearing loss was associated with DSPN, low high-density lipoprotein (HDL) cholesterol levels, and coronary heart disease. Interestingly, there was no association of hearing loss with either the duration of diabetes or the degree of glucose control.

### Cardiovascular Autonomic Neuropathy

#### Incidence and Prevalence

The incidence and prevalence of CAN have varied substantially among studies. Such data are highly dependent on the diagnostic criteria, type of tests, definitions of normal, and patient characteristics (27). Among the DCCT participants who had normal autonomic function at baseline, <10% of the conventional and <5% of intensive treatment groups were found to have CAN after approximately 6 years of follow-up (1,3). In contrast, in a European cohort of patients with diabetes contemporary with the DCCT cohort, abnormalities in individual indices of heart rate variability were reported in up to 31% (131).

CAN increases substantially with diabetes duration regardless of type of diabetes (5,23,28,132). Evaluations performed after 13–14 years of follow-up of the DCCT participants enrolled in the EDIC study demonstrated CAN prevalence rates as high as 35% in the conventionally treated cohort (5). In the EURODIAB study, autonomic dysfunction was present in one-third of type 1 diabetes patients at follow-up (133). Prevalence rates of 60% and higher were reported in cohorts of patients with longstanding type 2 diabetes (28,53,134) and in patients with longstanding type 1 diabetes who were candidates for a potential pancreas transplantation (135).

Estimates of prevalence for other manifestations of DAN, such as gastrointestinal manifestations, bladder dysfunction, and erectile dysfunction, have been reported to be at least 25% or higher in populations with longstanding type 1 diabetes or type 2 diabetes that have been studied (30,63).

Temporal trends should also be considered. Among those with a 20-year duration of type 1 diabetes in the EDC, the incidence of symptomatic autonomic neuropathy steadily declined comparing those diagnosed between 1965 and 1969 with those diagnosed between 1975 and 1980 (p<0.05). However, the difference in the decline among those with a 25-year duration was borderline (p<0.06) (102).

#### Natural History

The natural history of CAN is not well defined. Changes in CAN measures and a possible shift in the sympathetic/parasympathetic balance favoring sympathetic tone were described in individuals with glucose values in a prediabetes range in the Framingham Heart Study (136). Abnormalities have also been observed in cohorts of individuals with impaired glucose tolerance (71,137).

Although overt clinical manifestations of CAN are not usually present at the time of diagnosis of diabetes, abnormalities such as changes in HRV or CART can be present early in its course. Children with diabetes have consistently been found to have higher average heart rates than those without diabetes (138,139). The basis for the increased heart rate is unknown, but a relation to autonomic dysfunction is a possibility.

#### Risk Factors

The DCCT demonstrated that intensive glucose management for type 1 diabetes reduced the incidence of CAN by 53% compared to conventional therapy (1,3). During EDIC, CAN progressed substantially in both formerly treated groups, but the prevalence and incidence of CAN in EDIC remained significantly lower in the group that had been intensively treated than in the group that had been conventionally treated, in spite of an equalization in the A1c between groups starting at EDIC year 5 (5). This suggests that metabolic memory could be a determinant of CAN. Treatment group differences in the mean A1c level during DCCT and EDIC explained virtually all of the beneficial effect of intensive therapy on the risk of incident CAN. This finding supports the view that intensive treatment of type 1 diabetes should be initiated as early as is safely possible.

In contrast to the DCCT, randomized clinical trials of type 2 diabetes patients tend to show little evidence of an association between CAN and the degree of glycemia. After 10 years of follow-up in the UKPDS, there was no difference between the intervention and control groups. The VA Cooperative Study demonstrated no difference in the prevalence of autonomic neuropathy in type 2 diabetes patients after 2 years of tight glycemic control compared to those without tight control (140). Similar results were reported by the VADT (121), although there is a question as to whether the CAN outcome measures were sufficiently sensitive. In a trial of type 2 diabetes Japanese patients (79), there were no significant differences in the prevalence of postural hypotension or abnormal heart rate variation between the intensively and conventionally treated groups.

TABLE 23.5 Mean Heart Rate Among Adults Age ≥40 Years, by Diabetes Status, Age, and Race/Ethnicity, U.S., 1999–2004

CHARACTERISTICS | MEAN HEART RATE IN BEATS PER MINUTE (STANDARD ERROR)
CHARACTERISTICS | Diagnosed Diabetes | Undiagnosed Diabetes | Prediabetes | Normal Glucose Levels
All | 75.8 (0.48)^*^ | 73.9 (1.22)^*^ | 70.5 (0.43)^†^ | 68.9 (0.40)
Age (years)
40–64 | 78.2 (0.70)^*^ | 74.6 (1.64)^‡^ | 70.9 (0.57)^‡^ | 69.2 (0.43)
≥65 | 72.7 (0.67)^*^ | 72.9 (1.62)^‡^ | 69.6 (0.51)^†^ | 67.7 (0.55)
Race/ethnicity
Non-Hispanic white | 76.1 (0.66)^*^ | 73.6 (1.45)^‡^ | 70.7 (0.52)^‡^ | 69.1 (0.43)
Non-Hispanic black | 75.8 (0.76)^*^ | 73.9 (1.53)^‡^ | 70.8 (1.13) | 68.4 (0.57)
Hispanic | 74.9 (0.91)^*^ | 74.5 (2.31)^‡^ | 69.1 (0.56)^‡^ | 66.7 (0.60)

Diagnosed diabetes is based on self-report. Undiagnosed diabetes is based on FPG ≥126 mg/dL or A1c ≥6.5%; prediabetes is based on FPG 100–125 mg/dL and/or A1c 5.7%–6.4%; and normal glucose is based on FPG <100 mg/dL and A1c <5.7%. Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; FPG, fasting plasma glucose.

* p<0.001 compared to persons with normal glucose levels

† p<0.05

‡ p<0.01

SOURCE: National Health and Nutrition Examination Surveys 1999–2004

Associations between CAN and glucose levels have been found in observational studies of type 1 diabetes patients (133,141,142). Among young type 1 diabetes patients in the SEARCH for Diabetes in Youth Study, decreased HRV was more evident in those with A1c ≥7.5% (≥58 mmol/mol) (143). Data pertaining to a role of glucose variability in the pathophysiology of CAN are limited. However, in one study, CAN was not associated with glucose variability (123).

In studies of other risk factors, CAN has been associated with hypertension, lipid measures, smoking, and adiposity indexes (133,142), while the presence of autonomic dysfunction was associated with higher risk of developing diabetes (144). In the Steno-2 study, an intensive multifactorial cardiovascular risk intervention targeting glucose, blood pressure, lipids, smoking, and other lifestyle factors reduced the progression or the development of CAN among type 2 diabetes patients with microalbuminuria (88). A beneficial effect of the intensive glycemic intervention alone on CAN was not clearly evident.

The impact of lifestyle interventions in preventing the progression of CAN was evident in patients with impaired glucose tolerance participating in the Diabetes Prevention Program (71), and population-based studies suggest that higher activity levels have beneficial effects on cardiovascular autonomic function (145). In another study, weight loss in obese patients was accompanied by improvement in cardiovascular autonomic function (89). Another study showed an association between DAN and lower income (146).

#### Association Between Heart Rate and Hyperglycemia

In a new analysis for Diabetes in America, NHANES 1999–2004 data were used to examine the association between heart rate and hyperglycemia. The sitting heart rate was measured for 60 seconds in NHANES participants age ≥40 years with diagnosed diabetes, previously undiagnosed diabetes (i.e., diagnosed at their NHANES visit by fasting plasma glucose [FPG] ≥126 mg/dL [≥6.99 mmol/L] or A1c ≥6.5% [≥48 mmol/mol]), prediabetes (FPG 100–125 mg/dL [5.55–6.94 mmol/L] and/or A1c 5.7%–6.4% [39–46 mmol/L]), or normal glucose levels (FPG <100 mg/dL and A1c <5.7%). Table 23.5 shows the mean heart rate according to the state of glycemia. The heart rate was significantly higher in those with diagnosed diabetes than in those with normal glucose levels (75.8 vs. 68.9 beats per minute, p<0.001). These trends were also evident when age and race/ethnicity subgroups were analyzed. Mean heart rate was higher among those with undiagnosed diabetes and those with prediabetes compared to those with normal glucose levels (73.9 and 70.5 vs. 68.9 beats per minute, respectively, p<0.001 and p<0.05). Among those with diagnosed diabetes, there was a trend for higher heart rates with increasing A1c values (Table 23.6), but there was no trend for fasting plasma glucose levels (data not shown).

TABLE 23.6 Mean Heart Rate Among Adults Age ≥40 Years With Diagnosed Diabetes, by A1c Value, U.S., 1999–2004

MEAN HEART RATE IN BEATS PER MINUTE (STANDARD ERROR)
Diagnosed Diabetes, A1c | | | | Normal Glucose Levels
<7.0% | ≥7.0%–<9.0% | ≥9.0%–<11.0% | ≥11.0% | Normal Glucose Levels
74.1 (0.65)^*^ | 75.2 (0.94)^*^ | 80.4 (1.33)^*^ | 85.0 (0.40)^*^ | 68.9 (0.40)

Diagnosed diabetes is based on self-report. Normal glucose is based on fasting plasma glucose <100 mg/dL and A1c <5.7%. Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin.

* p<0.001 compared to persons with normal glucose levels

SOURCE: National Health and Nutrition Examination Surveys 1999–2004

The data suggest that a decreased plasma volume does not explain higher heart rates in diabetic individuals. If that were the explanation, one would expect the more contemporaneous fasting glucose to be associated with heart rate rather than the A1c value. Also, it is doubtful that the minor glucose elevation in the prediabetic group would result in a decreased plasma volume. Although the analysis suggests that subtle autonomic dysfunction is an explanation for the elevated heart rate in diabetes, a direct effect of hyperglycemia on heart rate and myocardial dysfunction could still be a factor.

## Secondary Complications: Diabetic Foot Ulcers/Charcot Neuroarthropathy

Although end-stage complications of diabetic neuropathies, including foot ulceration and Charcot neuroarthropathy, are discussed in detail in Chapter 20 Peripheral Arterial Disease, Foot Ulcers, Lower Extremity Amputations, and Diabetes, brief mention is made here. Several longitudinal studies have confirmed that DSPN is a major contributory factor in the pathogenesis of foot ulceration in diabetes (8,24,44,45). Screening of all patients with diabetes at least annually is recommended for identification of neuropathic feet at risk of ulceration (45). The ADA recommends that a simple clinical examination should be sufficient to identify the patient at risk of ulceration: for neuropathy, the use of monofilaments, plus one other test that might include simple vibration perception using a tuning fork or pin-prick, is sufficient (45). Any patient found to have neuropathy of sufficient severity to put them at risk of foot ulceration requires education in preventive foot care and podiatric care (45).

Charcot neuroarthropathy is much less common than foot ulceration but is a clinically important and potentially devastating disorder; in the 21st century, diabetes is the most common cause of this condition in Western countries (147). A high degree of awareness and suspicion may enable early diagnosis and effective intervention. Any patient with known neuropathy who has a unilateral, unexplained, swollen, warm foot should be considered to have acute Charcot neuroarthropathy until proven otherwise.

The epidemiology of diabetic foot ulcers is discussed in Chapter 20. As indicated in that chapter, estimates of foot ulcers vary depending on the national survey used to report the data. Based on data from the Behavioral Risk Factor Surveillance System 2000–2007, for which foot lesions were self-reported as ever having lesions that took more than 4 weeks to heal, prevalence was appreciable (11.0%–13.0%) among telephone-interviewed diabetic participants age ≥18 years (Table 20.20). Data from the National Hospital Discharge Survey, which is based on estimates of the percentage of hospital discharges that list foot ulcers, indicated that in 2002–2009, foot ulcers were listed in 4.2% of discharges. The percentage decreased to 0.7% of discharges that did not list diabetes (Table 20.19).

Although several risk factors for diabetic foot ulcers have been identified, DSPN is perhaps the most important. This was strongly supported by evidence of an association between foot ulcers and the extent of vibration insensitivity in a case-control study (148). Moreover, prospective data have shown that DSPN is predictive of foot ulceration (149,150). Evidence suggests a pathogenetic sequence of hypoesthesia, increased plantar pressures, and finally, foot ulceration (151,152).

## Conclusions

Even though the observed frequencies of diabetic neuropathy vary according to several factors, it is clearly a common complication of diabetes. Among risk factors for diabetic neuropathy that have been identified, several are modifiable. Among these, glycemia appears to be the most impactful with regard to the occurrence and progression of neuropathy. However, important questions remain regarding the influence of glycemia on neuropathy. These include: (1) Is there truly a metabolic memory, and if so, when is it most significant during pathogenesis? (2) Is the effect of hyperglycemia simply a matter of its degree and duration or are other factors important, such as glucose variability? (3) To what extent is the effect of hyperglycemia modified by genetic factors and constitutional factors, such as nerve length? Other modifiable risk factors also require further study.

Diabetic neuropathy and its sequelae can have a major impact on the health and quality of life of those afflicted. Much has been learned about the disorder, but there is clearly a need to learn a great deal more, so that diabetic neuropathy can be effectively prevented and treated.

## List of Abbreviations

A1c: glycosylated hemoglobin
ACCORD: Action to Control Cardiovascular Risk in Diabetes
ADA: American Diabetes Association
BARI 2D: Bypass Angioplasty Revascularization Investigation 2 Diabetes trial
CAN: cardiovascular autonomic neuropathy
CART: cardiovascular autonomic reflex test
CASE: computer assisted sensory examination
CCM: corneal confocal microscopy
CI: confidence interval
CIDP: chronic inflammatory demyelinating polyneuropathy
DAN: diabetic autonomic neuropathy
DCCT: Diabetes Control and Complications Trial
DRPN: diabetic radiculoplexus neuropathy
DSPN: distal symmetrical polyneuropathy
ECG: electrocardiogram
EDC: Epidemiology of Diabetes Complications study
EDIC: Epidemiology of Diabetes Interventions and Complications study
ER: endoplasmic reticulum
FPG: fasting plasma glucose
HRV: heart rate variability
IENFD: intra-epidermal nerve fiber density
MNSI: Michigan Neuropathy Screening Instrument
NHANES: National Health and Nutrition Examination Survey
NSS: Neuropathy Symptom Score
QST: quantitative sensory testing
SFN: small fiber neuropathies
UKPDS: United Kingdom Prospective Diabetes Study
VADT: Veterans Affairs Diabetes Trial
WESDR: Wisconsin Epidemiologic Study of Diabetic Retinopathy

## References

1 The effect of intensive treatment of diabetes on the development and progression of long-term complications in insulin-dependent diabetes mellitus. The Diabetes Control and Complications Trial Research Group. N Engl J Med 329:977–986, 1993 8366922
2 Effect of intensive diabetes treatment on nerve conduction in the Diabetes Control and Complications Trial. Ann Neurol 38:869–880, 1995 8526459
3 The effect of intensive diabetes therapy on measures of autonomic nervous system function in the Diabetes Control and Complications Trial (DCCT). Diabetologia 41:416–423, 1998 9562345
4 Albers JW, Herman WH, Pop-Busui R, Feldman EL, Martin CL, Cleary PA, Waberski BH, Lachin JM; Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Research Group: Effect of prior intensive insulin treatment during the Diabetes Control and Complications Trial (DCCT) on peripheral neuropathy in type 1 diabetes during the Epidemiology of Diabetes Interventions and Complications (EDIC) Study. Diabetes Care 33:1090–1096, 2010 20150297
5 Pop-Busui R, Low PA, Waberski BH, Martin CL, Albers JW, Feldman EL, Sommer C, Cleary PA, Lachin JM, Herman WH; DCCT/EDIC Research Group: Effects of prior intensive insulin therapy on cardiac autonomic nervous system function in type 1 diabetes mellitus: the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study (DCCT/EDIC). Circulation 119:2886–2893, 2009 19470886
6 Harris M, Eastman R, Cowie C: Symptoms of sensory neuropathy in adults with NIDDM in the U.S. population. Diabetes Care 16:1446–1452, 1993 8299433
7 Partanen J, Niskanen L, Lehtinen J, Mervaala E, Siitonen O, Uusitupa M: Natural history of peripheral neuropathy in patients with non-insulin-dependent diabetes mellitus. N Engl J Med 333:89–94, 1995 7777034
8 Boulton AJ, Vileikyte L, Ragnarson-Tennvall G, Apelqvist J: The global burden of diabetic foot disease. Lancet 366:1719–1724, 2005 16291066
9 Vileikyte L: Diabetic foot ulcers: a quality of life issue. Diabetes Metab Res Rev 17:246–249, 2001 11544609
10 Vileikyte L, Leventhal H, Gonzalez JS, Peyrot M, Rubin RR, Ulbrecht JS, Garrow A, Waterman C, Cavanagh PR, Boulton AJ: Diabetic peripheral neuropathy and depressive symptoms: the association revisited. Diabetes Care 28:2378–2383, 2005 16186266
11 Vileikyte L, Rubin RR, Leventhal H: Psychological aspects of diabetic neuropathic foot complications: an overview. Diabetes Metab Res Rev 20(Suppl 1):S13–S18, 2004
12 Boulton AJ, Gries FA, Jervell JA: Guidelines for the diagnosis and outpatient management of diabetic peripheral neuropathy. Diabet Med 15:508–514, 1998 9632127
13 Boulton AJ, Vinik AI, Arezzo JC, Bril V, Feldman EL, Freeman R, Malik RA, Maser RE, Sosenko JM, Ziegler D; American Diabetes Association: Diabetic neuropathies: a statement by the American Diabetes Association. Diabetes Care 28:956–962, 2005 15793206
14 Tesfaye S, Boulton AJ, Dyck PJ, Freeman R, Horowitz M, Kempler P, Lauria G, Malik RA, Spallone V, Vinik A, Bernardi L, Valensi P; Toronto Diabetic Neuropathy Expert Group: Diabetic neuropathies: update on definitions, diagnostic criteria, estimation of severity, and treatments. Diabetes Care 33:2285–2293, 2010 20876709
15 Pop-Busui R, Boulton AJ, Feldman EL, Bril V, Freeman R, Malik RA, Sosenko JM, Ziegler D: Diabetic Neuropathy: A position statement by the American Diabetes Association. Diabetes Care 40:136–154, 2017 27999003
16 Boulton AJ, Valensi P, Tesfaye S: International Neuropathy Workshop of 2009: introduction to the final reports. Diabetes Metab Res Rev 27:617–619, 2011 21695765
17 Consensus statement: report and recommendations of the San Antonio conference on diabetic neuropathy. American Diabetes Association; American Academy of Neurology. Diabetes Care 11:592–597, 1988 3060328
18 Dyck PJ, Albers JW, Andersen H, Arezzo JC, Biessels GJ, Bril V, Feldman EL, Litchy WJ, O’Brien PC, Russell JW; Toronto Expert Panel on Diabetic Neuropathy: Diabetic polyneuropathies: update on research definition, diagnostic criteria and estimation of severity. Diabetes Metab Res Rev 27:620–628, 2011 21695763
19 Albers JW, Pop-Busui R: Diabetic neuropathy: mechanisms, emerging treatments, and subtypes. Curr Neurol Neurosci Rep 14:473, 2014 24954624
20 Malik RA, Veves A, Tesfaye S, Smith G, Cameron N, Zochodne D, Lauria G; Toronto Consensus Panel on Diabetic Neuropathy: Small fibre neuropathy: role in the diagnosis of diabetic sensorimotor polyneuropathy. Diabetes Metab Res Rev 27:678–684, 2011 21695760
21 Smith AG, Singleton JR: Diabetic neuropathy. Continuum (Minneap Minn) 18:60–84, 2012 22810070
22 Callaghan BC, Kerber KA, Lisabeth LL, Morgenstern LB, Longoria R, Rodgers A, Longwell P, Feldman EL: Role of neurologists and diagnostic tests on the management of distal symmetric polyneuropathy. JAMA Neurol 71:1143–1149, 2014 25048157
23 Pop-Busui R: What do we know and we do not know about cardiovascular autonomic neuropathy in diabetes. J Cardiovasc Transl Res 5:463–478, 2012 22644723
24 Boulton AJ, Malik RA, Arezzo JC, Sosenko JM: Diabetic somatic neuropathies. Diabetes Care 27:1458–1486, 2004 15161806
25 Tesfaye S, Kempler P: Painful diabetic neuropathy. Diabetologia 48:805–807, 2005 15834549
26 Gibbons CH, Freeman R: Treatment-induced diabetic neuropathy: a reversible painful autonomic neuropathy. Ann Neurol 67:534–541, 2010 20437589
27 Ang L, Jaiswal M, Martin C, Pop-Busui R: Glucose control and diabetic neuropathy: lessons from recent large clinical trials. Curr Diab Rep 14:528, 2014 25139473
28 Spallone V, Ziegler D, Freeman R, Bernardi L, Frontoni S, Pop-Busui R, Stevens M, Kempler P, Hilsted J, Tesfaye S, Low P, Valensi P; Toronto Consensus Panel on Diabetic Neuropathy: Cardiovascular autonomic neuropathy in diabetes: clinical impact, assessment, diagnosis, and management. Diabetes Metab Res Rev 27:639–653, 2011 21695768
29 Vinik AI, Ziegler D: Diabetic cardiovascular autonomic neuropathy. Circulation 115:387–397, 2007 17242296
30 Kempler P, Amarenco G, Freeman R, Frontoni S, Horowitz M, Stevens M, Low P, Pop-Busui R, Tahrani AA, Tesfaye S, Varkonyi T, Ziegler D, Valensi P; Toronto Consensus Panel on Diabetic Neuropathy: Management strategies for gastrointestinal, erectile, bladder, and sudomotor dysfunction in patients with diabetes. Diabetes Metab Res Rev 27:665–677, 2011 21748841
31 Bharucha AE: Epidemiology and natural history of gastroparesis. Gastroenterol Clin North Am 44:9–19, 2015 25667019
32 Soykan I, Sivri B, Sarosiek I, Kiernan B, McCallum RW: Demography, clinical characteristics, psychological and abuse profiles, treatment, and long-term follow-up of patients with gastroparesis. Dig Dis Sci 43:2398–2404, 1998 9824125
33 Jung HK, Choung RS, Locke GR 3rd, Schleck CD, Zinsmeister AR, Szarka LA, Mullan B, Talley NJ: The incidence, prevalence, and outcomes of patients with gastroparesis in Olmsted County, Minnesota, from 1996 to 2006. Gastroenterology 136:1225–1233, 2009 19249393
34 Choung RS, Locke GR 3rd, Schleck CD, Zinsmeister AR, Melton LJ 3rd, Talley NJ: Risk of gastroparesis in subjects with type 1 and 2 diabetes in the general population. Am J Gastroenterol 107:82–88, 2012 22085818
35 Low PA, Denq JC, Opfer-Gehrking TL, Dyck PJ, O’Brien PC, Slezak JM: Effect of age and gender on sudomotor and cardiovagal function and blood pressure response to tilt in normal subjects. Muscle Nerve 20:1561–1568, 1997 9390669
36 Dyck PJ: Severity and staging of diabetic polyneuropathy. In Textbook of Diabetic Neuropathy. Gries FA, Cameron NE, Low PA, Ziegler D, Eds. Stuttgart, Thieme, 2003, p. 170–175
37 Diabetic polyneuropathy in controlled clinical trials: consensus report of the Peripheral Nerve Society. Ann Neurol 38:478–482, 1995 7668839
38 Herman WH, Pop-Busui R, Braffett BH, Martin CL, Cleary PA, Albers JW, Feldman EL; DCCT/EDIC Research Group: Use of the Michigan Neuropathy Screening Instrument as a measure of distal symmetrical peripheral neuropathy in type 1 diabetes: results from the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications. Diabet Med 29:937–944, 2012 22417277
39 Martin CL, Albers J, Herman WH, Cleary P, Waberski B, Greene DA, Stevens MJ, Feldman EL; DCCT/EDIC Research Group: Neuropathy among the Diabetes Control and Complications Trial cohort 8 years after trial completion. Diabetes Care 29:340–344, 2006 16443884
40 Vileikyte L, Peyrot M, Bundy C, Rubin RR, Leventhal H, Mora P, Shaw JE, Baker P, Boulton AJ: The development and validation of a neuropathy- and foot ulcer-specific quality of life instrument. Diabetes Care 26:2549–2555, 2003 12941717
41 Feldman EL, Stevens MJ, Thomas PK, Brown MB, Canal N, Greene DA: A practical two-step quantitative clinical and electrophysiological assessment for the diagnosis and staging of diabetic neuropathy. Diabetes Care 17:1281–1289, 1994 7821168
42 Vinik EJ, Hayes RP, Oglesby A, Bastyr E, Barlow P, Ford-Molvik SL, Vinik AI: The development and validation of the Norfolk QOL-DN, a new measure of patients’ perception of the effects of diabetes and diabetic neuropathy. Diabetes Technol Ther 7:497–508, 2005 15929681
43 Pop-Busui R, Lu J, Lopes N, Jones TL; BARI 2D Investigators: Prevalence of diabetic peripheral neuropathy and relation to glycemic control therapies at baseline in the BARI 2D cohort. J Peripher Nerv Syst 14:1–13, 2009
44 Abbott CA, Carrington AL, Ashe H, Bath S, Every LC, Griffiths J, Hann AW, Hussein A, Jackson N, Johnson KE, Ryder CH, Torkington R, Van Ross ER, Whalley AM, Widdows P, Williamson S, Boulton AJ; North-West Diabetes Foot Care Study: The North-West Diabetes Foot Care Study: incidence of, and risk factors for, new diabetic foot ulceration in a community-based patient cohort. Diabet Med 19:377–384, 2002 12027925
45 Boulton AJ, Armstrong DG, Albert SF, Frykberg RG, Hellman R, Kirkman MS, Lavery LA, Lemaster JW, Mills JL, Sr., Mueller MJ, Sheehan P, Wukich DK; American Diabetes Association; American Association of Clinical Endocrinologists: Comprehensive foot examination and risk assessment: a report of the task force of the foot care interest group of the American Diabetes Association, with endorsement by the American Association of Clinical Endocrinologists. Diabetes Care 31:1679–1685, 2008 18663232
46 Bowling FL, Abbott CA, Harris WE, Atanasov S, Malik RA, Boulton AJ: A pocket-sized disposable device for testing the integrity of sensation in the outpatient setting. Diabet Med 29:1550–1552, 2012 22672290
47 Dyck PJ, Albers JW, Wolfe J, Bolton CF, Walsh N, Klein CJ, Zafft AJ, Russell JW, Thomas K, Davies JL, Carter RE, Melton LJ 3rd, Litchy WJ; Clinical vs. Neurophysiology Trial 3 Investigators: A trial of proficiency of nerve conduction: greater standardization still needed. Muscle Nerve 48:369–374, 2013 23861198
48 Dyck PJ, Norell JE, Tritschler H, Schuette K, Samigullin R, Ziegler D, Bastyr EJ 3rd, Litchy WJ, O’Brien PC: Challenges in design of multicenter trials: end points assessed longitudinally for change and monotonicity. Diabetes Care 30:2619–2625, 2007 17513707
49 Dyck PJ, Overland CJ, Low PA, Litchy WJ, Davies JL, Dyck PJ, O’Brien PC; Cl vs. NPhys Trial Investigators, Albers JW, Andersen H, Bolton CF, England JD, Klein CJ, Llewelyn JG, Mauermann ML, Russell JW, Singer W, Smith AG, Tesfaye S, Vella A: Signs and symptoms versus nerve conduction studies to diagnose diabetic sensorimotor polyneuropathy: Cl vs. NPhys trial. Muscle Nerve 42:157–164, 2010 20658599
50 Quattrini C, Harris ND, Malik RA, Tesfaye S: Impaired skin microvascular reactivity in painful diabetic neuropathy. Diabetes Care 30:655–659, 2007 17327336
51 Malik RA, Kallinikos P, Abbott CA, van Schie CH, Morgan P, Efron N, Boulton AJ: Corneal confocal microscopy: a non-invasive surrogate of nerve fibre damage and repair in diabetic patients. Diabetologia 46:683–688, 2003 12739016
52 Tavakoli M, Mitu-Pretorian M, Petropoulos IN, Fadavi H, Asghar O, Alam U, Ponirakis G, Jeziorska M, Marshall A, Efron N, Boulton AJ, Augustine T, Malik RA: Corneal confocal microscopy detects early nerve regeneration in diabetic neuropathy after simultaneous pancreas and kidney transplantation. Diabetes 62:254–260, 2013 23002037
53 Low PA, Benrud-Larson LM, Sletten DM, Opfer-Gehrking TL, Weigand SD, O’Brien PC, Suarez GA, Dyck PJ: Autonomic symptoms and diabetic neuropathy: a population-based study. Diabetes Care 27:2942–2947, 2004 15562211
54 Assessment: clinical autonomic testing report of the Therapeutics and Technology Assessment Subcommittee of the American Academy of Neurology. Neurology 46:873–880, 1996 8618715
55 Ewing DJ, Clarke BF: Diagnosis and management of diabetic autonomic neuropathy. Br Med J (Clin Res Ed) 285:916–918, 1982
56 Ewing DJ, Campbell IW, Clarke BF: Assessment of cardiovascular effects in diabetic autonomic neuropathy and prognostic implications. Ann Intern Med 92:308–311, 1980 7356219
57 England JD, Gronseth GS, Franklin G, Carter GT, Kinsella LJ, Cohen JA, Asbury AK, Szigeti K, Lupski JR, Latov N, Lewis RA, Low PA, Fisher MA, Herrmann DN, Howard JF, Jr., Lauria G, Miller RG, Polydefkis M, Sumner AJ; American Academy of Neurology: Practice parameter: evaluation of distal symmetric polyneuropathy: role of autonomic testing, nerve biopsy, and skin biopsy (an evidence-based review). Report of the American Academy of Neurology, American Association of Neuromuscular and Electrodiagnostic Medicine, and American Academy of Physical Medicine and Rehabilitation. Neurology 72:177–184, 2009 19056667
58 Bernardi L, Spallone V, Stevens M, Hilsted J, Frontoni S, Pop-Busui R, Ziegler D, Kempler P, Freeman R, Low P, Tesfaye S, Valensi P; Toronto Consensus Panel on Diabetic Neuropathy: Methods of investigation methods for cardiac autonomic function in human research studies. Diabetes Metab Res Rev 27:654–664, 2011 21695761
59 Vinik AI, Maser RE, Ziegler D: Autonomic imbalance: prophet of doom or scope for hope? Diabet Med 28:643–651, 2011 21569084
60 Heart rate variability: standards of measurement, physiological interpretation and clinical use. Task Force of the European Society of Cardiology and the North American Society of Pacing and Electrophysiology. Circulation 93:1043–1065, 1996 8598068
61 Edwards JL, Vincent AM, Cheng HT, Feldman EL: Diabetic neuropathy: mechanisms to management. Pharmacol Ther 120:1–34, 2008 18616962
62 Pacher P, Liaudet L, Soriano FG, Mabley JG, Szabo E, Szabo C: The role of poly(ADP-ribose) polymerase activation in the development of myocardial and endothelial dysfunction in diabetes. Diabetes 51:514–521, 2002 11812763
63 Vinik AI, Maser RE, Mitchell BD, Freeman R: Diabetic autonomic neuropathy. Diabetes Care 26:1553–1579, 2003 12716821
64 Witzke KA, Vinik AI, Grant LM, Grant WP, Parson HK, Pittenger GL, Burcus N: Loss of RAGE defense: a cause of Charcot neuroarthropathy? Diabetes Care 34:1617–1621, 2011 21593297
65 O’Brien PD, Hinder LM, Sakowski SA, Feldman EL: ER stress in diabetic peripheral neuropathy: a new therapeutic target. Antioxid Redox Signal 21:621–633, 2014 24382087
66 Cameron NE, Cotter MA: Pro-inflammatory mechanisms in diabetic neuropathy: focus on the nuclear factor kappa B pathway. Curr Drug Targets 9:60–67, 2008 18220713
67 Wang Y, Schmeichel AM, Iida H, Schmelzer JD, Low PA: Enhanced inflammatory response via activation of NF-kappaB in acute experimental diabetic neuropathy subjected to ischemia-reperfusion injury. J Neurol Sci 247:47–52, 2006 16631800
68 Kellogg AP, Wiggin TD, Larkin DD, Hayes JM, Stevens MJ, Pop-Busui R: Protective effects of cyclooxygenase-2 gene inactivation against peripheral nerve dysfunction and intraepidermal nerve fibers loss in experimental diabetes. Diabetes 56:2997–3005, 2007 17720896
69 Fernyhough P, Roy Chowdhury SK, Schmidt RE: Mitochondrial stress and the pathogenesis of diabetic neuropathy. Expert Rev Endocrinol Metab 5:39–49, 2010 20729997
70 Ma J, Farmer KL, Pan P, Urban MJ, Zhao H, Blagg BS, Dobrowsky RT: Heat shock protein 70 is necessary to improve mitochondrial bioenergetics and reverse diabetic sensory neuropathy following KU-32 therapy. J Pharmacol Exp Ther 348:281–292, 2014 24263156
71 Carnethon MR, Prineas RJ, Temprosa M, Zhang ZM, Uwaifo G, Molitch ME; Diabetes Prevention Program Research Group: The association among autonomic nervous system function, incident diabetes, and intervention arm in the Diabetes Prevention Program. Diabetes Care 29:914–919, 2006 16567837
72 Singleton JR, Smith AG, Russell J, Feldman EL: Polyneuropathy with impaired glucose tolerance: implications for diagnosis and therapy. Curr Treat Options Neurol 7:33–42, 2005 15610705
73 Chang CJ, Yang YC, Lu FH, Lin TS, Chen JJ, Yeh TL, Wu CH, Wu JS: Altered cardiac autonomic function may precede insulin resistance in metabolic syndrome. Am J Med 123:432–438, 2010 20399320
74 Lieb DC, Parson HK, Mamikunian G, Vinik AI: Cardiac autonomic imbalance in newly diagnosed and established diabetes is associated with markers of adipose tissue inflammation. Exp Diabetes Res 2012:878760, 2012 22110481
75 Tesfaye S, Vileikyte L, Rayman G, Sindrup S, Perkins BA, Baconja M, Vinik AI, Boulton AJ; Toronto Expert Panel on Diabetic Neuropathy: Painful diabetic peripheral neuropathy: consensus recommendations on diagnosis, assessment and management. Diabetes Metab Res Rev 27:629–638, 2011 21695762
76 Klein R, Klein BE, Moss SE: Relation of glycemic control to diabetic microvascular complications in diabetes mellitus. Ann Intern Med 124:90–96, 1996 8554220
77 Maser RE, Steenkiste AR, Dorman JS, Nielsen VK, Bass EB, Manjoo Q, Drash AL, Becker DJ, Kuller LH, Greene DA, Orchard TJ: Epidemiological correlates of diabetic neuropathy. Report from Pittsburgh Epidemiology of Diabetes Complications Study. Diabetes 38:1456–1461, 1989 2620781
78 Martin CL, Albers JW, Pop-Busui R; DCCT/EDIC Research Group: Neuropathy and related findings in the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications study. Diabetes Care 37:31–38, 2014 24356595
79 Ohkubo Y, Kishikawa H, Araki E, Miyata T, Isami S, Motoyoshi S, Kojima Y, Furuyoshi N, Shichiri M: Intensive insulin therapy prevents the progression of diabetic microvascular complications in Japanese patients with non-insulin-dependent diabetes mellitus: a randomized prospective 6-year study. Diabetes Res Clin Pract 28:103–117, 1995 7587918
80 Ismail-Beigi F, Craven T, Banerji MA, Basile J, Calles J, Cohen RM, Cuddihy R, Cushman WC, Genuth S, Grimm RH, Jr., Hamilton BP, Hoogwerf B, Karl D, Katz L, Krikorian A, O’Connor P, Pop-Busui R, Schubart U, Simmons D, Taylor H, Thomas A, Weiss D, Hramiak I; ACCORD Trial Group: Effect of intensive treatment of hyperglycaemia on microvascular outcomes in type 2 diabetes: an analysis of the ACCORD randomised trial. Lancet 376:419–430, 2010 20594588
81 Charles M, Ejskjaer N, Witte DR, Borch-Johnsen K, Lauritzen T, Sandbaek A: Prevalence of neuropathy and peripheral arterial disease and the impact of treatment in people with screen-detected type 2 diabetes: the ADDITION-Denmark study. Diabetes Care 34:2244–2249, 2011 21816977
82 Charles M, Fleischer J, Witte DR, Ejskjaer N, Borch-Johnsen K, Lauritzen T, Sandbaek A: Impact of early detection and treatment of diabetes on the 6-year prevalence of cardiac autonomic neuropathy in people with screen-detected diabetes: ADDITION-Denmark, a cluster-randomised study. Diabetologia 56:101–108, 2013 23064291
83 Intensive blood-glucose control with sulphonylureas or insulin compared with conventional treatment and risk of complications in patients with type 2 diabetes (UKPDS 33). UK Prospective Diabetes Study (UKPDS) Group. Lancet 352:837–853, 1998 9742976
84 Callaghan BC, Little AA, Feldman EL, Hughes RA: Enhanced glucose control for preventing and treating diabetic neuropathy. Cochrane Database Syst Rev 6:CD007543, 2012
85 Pop-Busui R, Lu J, Brooks MM, Albert S, Althouse AD, Escobedo J, Green J, Palumbo P, Perkins BA, Whitehouse F, Jones TL; BARI 2D Study Group: Impact of glycemic control strategies on the progression of diabetic peripheral neuropathy in the Bypass Angioplasty Revascularization Investigation 2 Diabetes (BARI 2D) cohort. Diabetes Care 36:3208–3215, 2013 23757426
86 Kluding PM, Pasnoor M, Singh R, Jernigan S, Farmer K, Rucker J, Sharma NK, Wright DE: The effect of exercise on neuropathic symptoms, nerve function, and cutaneous innervation in people with diabetic peripheral neuropathy. J Diabetes Complications 26:424–429, 2012 22717465
87 Smith AG, Russell J, Feldman EL, Goldstein J, Peltier A, Smith S, Hamwi J, Pollari D, Bixby B, Howard J, Singleton JR: Lifestyle intervention for pre-diabetic neuropathy. Diabetes Care 29:1294–1299, 2006 16732011
88 Gaede P, Vedel P, Larsen N, Jensen GV, Parving HH, Pedersen O: Multifactorial intervention and cardiovascular disease in patients with type 2 diabetes. N Engl J Med 348:383–393, 2003 12556541
89 Maser RE, Lenhard MJ: An overview of the effect of weight loss on cardiovascular autonomic function. Curr Diabetes Rev 3:204–211, 2007 18220673
90 Boulton AJ, Kempler P, Ametov A, Ziegler D: Whither pathogenetic treatments for diabetic polyneuropathy? Diabetes Metab Res Rev 29:327–333, 2013 23381942
91 Vincent AM, Callaghan BC, Smith AL, Feldman EL: Diabetic neuropathy: cellular mechanisms as therapeutic targets. Nat Rev Neurol 7:573–583, 2011 21912405
92 Ziegler D, Low PA, Litchy WJ, Boulton AJ, Vinik AI, Freeman R, Samigullin R, Tritschler H, Munzel U, Maus J, Schutte K, Dyck PJ: Efficacy and safety of antioxidant treatment with α-lipoic acid over 4 years in diabetic polyneuropathy: the NATHAN 1 trial. Diabetes Care 34:2054–2060, 2011 21775755
93 Ziegler D, Keller J, Maier C, Pannek J; German Diabetes Association: Diabetic neuropathy. Exp Clin Endocrinol Diabetes 122:406–415, 2014 25014092
94 Ziegler D, Nowak H, Kempler P, Vargha P, Low PA: Treatment of symptomatic diabetic polyneuropathy with the antioxidant alpha-lipoic acid: a meta-analysis. Diabet Med 21:114–121, 2004 14984445
95 Ekberg K, Brismar T, Johansson BL, Jonsson B, Lindstrom P, Wahren J: Amelioration of sensory nerve dysfunction by c-peptide in patients with type 1 diabetes. Diabetes 52:536–541, 2003 12540632
96 Ekberg K, Brismar T, Johansson BL, Lindstrom P, Juntti-Berggren L, Norrby A, Berne C, Arnqvist HJ, Bolinder J, Wahren J: C-peptide replacement therapy and sensory nerve function in type 1 diabetic neuropathy. Diabetes Care 30:71–76, 2007 17192336
97 Ziegler D, Movsesyan L, Mankovsky B, Gurieva I, Abylaiuly Z, Strokov I: Treatment of symptomatic polyneuropathy with actovegin in type 2 diabetic patients. Diabetes Care 32:1479–1484, 2009 19470838
98 Fonseca VA, Lavery LA, Thethi TK, Daoud Y, DeSouza C, Ovalle F, Denham DS, Bottiglieri T, Sheehan P, Rosenstock J: Metanx in type 2 diabetes with peripheral neuropathy: a randomized trial. Am J Med 126:141–149, 2013 23218892
99 Wahren J, Foyt H, Daniels M, Arezzo JC: Long-acting c-peptide and neuropathy in type 1 diabetes: a 12-month clinical trial. Diabetes Care 39:596–602, 2016 26884473
100 Sands ML, Shetterly SM, Franklin GM, Hamman RF: Incidence of distal symmetric (sensory) neuropathy in NIDDM. The San Luis Valley Diabetes Study. Diabetes Care 20:322–329, 1997 9051381
101 Sosenko JM, Gadia MT, Fournier AM, O’Connell MT, Aguiar MC, Skyler JS: Body stature as a risk factor for diabetic sensory neuropathy. Am J Med 80:1031–1034, 1986 3728501
102 Pambianco G, Costacou T, Ellis D, Becker DJ, Klein R, Orchard TJ: The 30-year natural history of type 1 diabetes complications: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes 55:1463–1469, 2006 16644706
103 Sorensen L, Molyneaux L, Yue DK: Insensate versus painful diabetic neuropathy: the effects of height, gender, ethnicity and glycaemic control. Diabetes Res Clin Pract 57:45–51, 2002 12007729
104 Cheng WY, Jiang YD, Chuang LM, Huang CN, Heng LT, Wu HP, Tai TY, Lin BJ: Quantitative sensory testing and risk factors of diabetic sensory neuropathy. J Neurol 246:394–398, 1999 10399873
105 Tesfaye S, Stevens LK, Stephenson JM, Fuller JH, Plater M, Ionescu-Tirgoviste C, Nuber A, Pozza G, Ward JD: Prevalence of diabetic peripheral neuropathy and its relation to glycaemic control and potential risk factors: the EURODIAB IDDM Complications Study. Diabetologia 39:1377–1384, 1996 8933008
106 Sosenko JM, Sparling YH, Hu D, Welty T, Howard BV, Lee E, Robbins DC: Use of the Semmes-Weinstein monofilament in the Strong Heart Study. Risk factors for clinical neuropathy. Diabetes Care 22:1715–1721, 1999 10526741
107 Bainbridge KE, Hoffman HJ, Cowie CC: Diabetes and hearing impairment in the United States: audiometric evidence from the National Health and Nutrition Examination Survey, 1999 to 2004. Ann Intern Med 149:1–10, 2008 18559825
108 Dabelea D, Stafford JM, Mayer-Davis EJ, D’Agostino R, Jr., Dolan L, Imperatore G, Linder B, Lawrence JM, Marcovina SM, Mottl AK, Black MH, Pop-Busui R, Saydah S, Hamman RF, Pihoker C; SEARCH for Diabetes in Youth Research Group: Association of type 1 diabetes vs type 2 diabetes diagnosed during childhood and adolescence with complications during teenage years and young adulthood. JAMA 317:825–835, 2017 28245334
109 Young MJ, Boulton AJ, MacLeod AF, Williams DR, Sonksen PH: A multicentre study of the prevalence of diabetic peripheral neuropathy in the United Kingdom hospital clinic population. Diabetologia 36:150–154, 1993 8458529
110 Grandinetti A, Chow DC, Sletten DM, Oyama JK, Theriault AG, Schatz IJ, Low PA: Impaired glucose tolerance is associated with postganglionic sudomotor impairment. Clin Auton Res 17:231–233, 2007 17717720
111 Singleton JR, Smith AG, Bromberg MB: Painful sensory polyneuropathy associated with impaired glucose tolerance. Muscle Nerve 24:1225–1228, 2001 11494277
112 Ziegler D, Rathmann W, Dickhaus T, Meisinger C, Mielck A; KORA Study Group: Prevalence of polyneuropathy in pre-diabetes and diabetes is associated with abdominal obesity and macroangiopathy: the MONICA/KORA Augsburg Surveys S2 and S3. Diabetes Care 31:464–469, 2008 18039804
113 Katon JG, Reiber GE, Nelson KM: Peripheral neuropathy defined by monofilament insensitivity and diabetes status: NHANES 1999–2004. Diabetes Care 36:1604–1606, 2013 23275365
114 Sosenko JM, Boulton AJ, Kubrusly DB, Weintraub JK, Skyler JS: The vibratory perception threshold in young diabetic patients: associations with glycemia and puberty. Diabetes Care 8:605–607, 1985 4075949
115 Ziegler D, Mayer P, Muhlen H, Gries FA: The natural history of somatosensory and autonomic nerve dysfunction in relation to glycaemic control during the first 5 years after diagnosis of type 1 (insulin-dependent) diabetes mellitus. Diabetologia 34:822–829, 1991 1769441
116 Sosenko JM, Kato M, Soto R, Goldberg RB: Sensory function at diagnosis and in early stages of NIDDM in patients detected through screening. Diabetes Care 15:847–852, 1992 1516503
117 Young RJ, Ewing DJ, Clarke BF: Chronic and remitting painful diabetic polyneuropathy. Correlations with clinical features and subsequent changes in neurophysiology. Diabetes Care 11:34–40, 1988 3338378
118 Laudadio C, Sima AA: Progression rates of diabetic neuropathy in placebo patients in an 18-month clinical trial. Ponalrestat Study Group. J Diabetes Complications 12:121–127, 1998 9618066
119 Sosenko JM, Kato M, Soto R, Bild DE: A prospective study of sensory function in patients with type 2 diabetes. Diabet Med 10:110–114, 1993 8458186
120 Tesfaye S, Chaturvedi N, Eaton SE, Ward JD, Manes C, Ionescu-Tirgoviste C, Witte DR, Fuller JH; EURODIAB Prospective Complications Study Group: Vascular risk factors and diabetic neuropathy. N Engl J Med 352:341–350, 2005 15673800
121 Duckworth W, Abraira C, Moritz T, Reda D, Emanuele N, Reaven PD, Zieve FJ, Marks J, Davis SN, Hayward R, Warren SR, Goldman S, McCarren M, Vitek ME, Henderson WG, Huang GD; VADT Investigators: Glucose control and vascular complications in veterans with type 2 diabetes. N Engl J Med 360:129–139, 2009 19092145
122 Pop-Busui R, Herman WH, Feldman EL, Low PA, Martin CL, Cleary PA, Waberski BH, Lachin JM, Albers JW; DCCT/EDIC Research Group: DCCT and EDIC studies in type 1 diabetes: lessons for diabetic neuropathy regarding metabolic memory and natural history. Curr Diab Rep 10:276–282, 2010 20464532
123 Bragd J, Adamson U, Backlund LB, Lins PE, Moberg E, Oskarsson P: Can glycaemic variability, as calculated from blood glucose self-monitoring, predict the development of complications in type 1 diabetes over a decade? Diabetes Metab 34:612–616, 2008 18824382
124 Siegelaar SE, Kilpatrick ES, Rigby AS, Atkin SL, Hoekstra JB, Devries JH: Glucose variability does not contribute to the development of peripheral and autonomic neuropathy in type 1 diabetes: data from the DCCT. Diabetologia 52:2229–2232, 2009 19672575
125 Adler AI, Boyko EJ, Ahroni JH, Stensel V, Forsberg RC, Smith DG: Risk factors for diabetic peripheral sensory neuropathy. Results of the Seattle Prospective Diabetic Foot Study. Diabetes Care 20:1162–1167, 1997 9203456
126 Wiles PG, Pearce SM, Rice PJ, Mitchell JM: Vibration perception threshold: influence of age, height, sex, and smoking, and calculation of accurate centile values. Diabet Med 8:157–161, 1991 1827402
127 Gragnoli C: PSMD9 is linked to type 2 diabetes neuropathy. J Diabetes Complications 25:329–331, 2011 21813292
128 Strokov IA, Bursa TR, Drepa OI, Zotova EV, Nosikov VV, Ametov AS: Predisposing genetic factors for diabetic polyneuropathy in patients with type 1 diabetes: a population-based case-control study. Acta Diabetol 40(Suppl 2):S375–S379, 2003 14704872
129 Mitchell BD, Hawthorne VM, Vinik AI: Cigarette smoking and neuropathy in diabetic patients. Diabetes Care 13:434–437, 1990 2318103
130 Bainbridge KE, Hoffman HJ, Cowie CC: Risk factors for hearing impairment among U.S. adults with diabetes: National Health and Nutrition Examination Survey 1999–2004. Diabetes Care 34:1540–1545, 2011 21593298
131 Ziegler D, Gries FA, Spuler M, Lessmann F: The epidemiology of diabetic neuropathy. Diabetic Cardiovascular Autonomic Neuropathy Multicenter Study Group. J Diabetes Complications 6:49–57, 1992 1562759
132 Pop-Busui R: Cardiac autonomic neuropathy in diabetes: a clinical perspective. Diabetes Care 33:434–441, 2010 20103559
133 Kempler P, Tesfaye S, Chaturvedi N, Stevens LK, Webb DJ, Eaton S, Kerenyi Z, Tamas G, Ward JD, Fuller JH; EURODIAB IDDM Complications Study Group: Autonomic neuropathy is associated with increased cardiovascular risk factors: the EURODIAB IDDM Complications Study. Diabet Med 19:900–909, 2002 12421426
134 Low PA: Diabetic autonomic neuropathy. Semin Neurol 16:143–151, 1996 8987128
135 Kennedy WR, Navarro X, Goetz FC, Sutherland DE, Najarian JS: Effects of pancreatic transplantation on diabetic neuropathy. N Engl J Med 322:1031–1037, 1990 2320063
136 Singh JP, Larson MG, O’Donnell CJ, Wilson PF, Tsuji H, Lloyd-Jones DM, Levy D: Association of hyperglycemia with reduced heart rate variability (The Framingham Heart Study). Am J Cardiol 86:309–312, 2000 10922439
137 Wu JS, Yang YC, Lin TS, Huang YH, Chen JJ, Lu FH, Wu CH, Chang CJ: Epidemiological evidence of altered cardiac autonomic function in subjects with impaired glucose tolerance but not isolated impaired fasting glucose. J Clin Endocrinol Metab 92:3885–3889, 2007 17666483
138 Barkai L, Madacsy L, Kassay L: Investigation of subclinical signs of autonomic neuropathy in the early stage of childhood diabetes. Horm Res 34:54–59, 1990 2097291
139 Sosenko JM, Boulton AJ, Kubrusly DB, Weintraub JK, Pasin RA, Schneiderman N, Skyler JS: Autonomic function and heart rate in young diabetic patients. J Pediatr Endocrinol 1:207–210, 1985
140 Azad N, Emanuele NV, Abraira C, Henderson WG, Colwell J, Levin SR, Nuttall FQ, Comstock JP, Sawin CT, Silbert C, Rubino FA: The effects of intensive glycemic control on neuropathy in the VA cooperative study on type II diabetes mellitus (VA CSDM). J Diabetes Complications 13:307–313, 1999 10765007
141 Solders G, Thalme B, Aguirre-Aquino M, Brandt L, Berg U, Persson A: Nerve conduction and autonomic nerve function in diabetic children. A 10-year follow-up study. Acta Paediatr 86:361–366, 1997 9174220
142 Voulgari C, Psallas M, Kokkinos A, Argiana V, Katsilambros N, Tentolouris N: The association between cardiac autonomic neuropathy with metabolic and other factors in subjects with type 1 and type 2 diabetes. J Diabetes Complications 25:159–167, 2011 20708417
143 Jaiswal M, Urbina EM, Wadwa RP, Talton JW, D’Agostino RB, Jr., Hamman RF, Fingerlin TE, Daniels S, Marcovina SM, Dolan LM, Dabelea D: Reduced heart rate variability among youth with type 1 diabetes: the SEARCH CVD study. Diabetes Care 36:157–162, 2013 22961570
144 Carnethon MR, Jacobs DR, Jr., Sidney S, Liu K; CARDIA study: Influence of autonomic nervous system dysfunction on the development of type 2 diabetes: the CARDIA study. Diabetes Care 26:3035–3041, 2003 14578236
145 Carnethon MR, Jacobs DR, Jr., Sidney S, Sternfeld B, Gidding SS, Shoushtari C, Liu K: A longitudinal study of physical activity and heart rate recovery: CARDIA, 1987–1993. Med Sci Sports Exerc 37:606–612, 2005 15809559
146 Secrest AM, Costacou T, Gutelius B, Miller RG, Songer TJ, Orchard TJ: Associations between socioeconomic status and major complications in type 1 diabetes: the Pittsburgh Epidemiology of Diabetes Complications (EDC) Study. Ann Epidemiol 21:374–381, 2011 21458731
147 Jeffcoate WJ: Charcot neuro-osteoarthropathy. Diabetes Metab Res Rev 24(Suppl 1):S62–S65, 2008 18393327
148 Boulton AJ, Kubrusly DB, Bowker JH, Gadia MT, Quintero L, Becker DM, Skyler JS, Sosenko JM: Impaired vibratory perception and diabetic foot ulceration. Diabet Med 3:335–337, 1986 2949922
149 Abbott CA, Vileikyte L, Williamson S, Carrington AL, Boulton AJ: Multicenter study of the incidence of and predictive risk factors for diabetic neuropathic foot ulceration. Diabetes Care 21:1071–1075, 1998 9653597
150 Lavery LA, Armstrong DG, Vela SA, Quebedeaux TL, Fleischli JG: Practical criteria for screening patients at high risk for diabetic foot ulceration. Arch Intern Med 158:157–162, 1998 9448554
151 Veves A, Murray HJ, Young MJ, Boulton AJ: The risk of foot ulceration in diabetic patients with high foot pressure: a prospective study. Diabetologia 35:660–663, 1992 1644245
152 Reiber GE, Vileikyte L, Boyko EJ, del Aguila M, Smith DG, Lavery LA, Boulton AJ: Causal pathways for incident lower-extremity ulcers in patients with diabetes from two settings. Diabetes Care 22:157–162, 1999 10333919