# CHAPTER 22 Kidney Disease in Diabetes

## Summary

Persons with diabetes make up the fastest growing group of kidney dialysis and transplant recipients in the United States. In 1985, when the first edition of Diabetes in America was published, 20,961 persons with diabetes were receiving renal replacement therapy, representing 29% of all new cases of end-stage renal disease (ESRD). By 2012, 239,837 persons with diabetes were on renal replacement therapy, accounting for 44% of all new ESRD cases. The increased count reflects growth in diabetes prevalence and increased access to dialysis and transplantation. Those with a primary diagnosis of diabetes have lower survival relative to other causes of ESRD, primarily because of the coexistent morbidity associated with diabetes, particularly cardiovascular diseases (CVD). While survival on dialysis has slowly improved across modalities since the 1990s, it remains reduced in persons with diabetes, half of whom die within 3 years of beginning dialysis in the United States. Similar to persons with ESRD in general, the leading causes of death among adults with diabetes who started dialysis in 1995–2009 were CVD (58% of the deaths) and infections (13% of the deaths). Kidney transplant recipients with diabetes have much better survival than those on dialysis, indicating a significant impact of the type of renal replacement therapy (transplant versus dialysis) on long-term survival.

Kidney failure affects about 1% of persons with diabetes in the United States. A considerably higher proportion, about 40%, have less severe kidney disease. Since the second edition of Diabetes in America was published in 1995, a wealth of new information has contributed substantially to the understanding of kidney disease associated with diabetes. In 2002, the National Kidney Foundation’s Kidney Disease Outcome Quality Initiative published a uniform definition of chronic kidney disease (CKD) and classification of its stages irrespective of underlying cause, thus providing a common language for defining both the severity and prognosis of kidney disease. The definition and classification of CKD were subsequently updated and refined by the Kidney Disease: Improving Global Outcomes in 2012. Accordingly, CKD is classified based on both albuminuria and glomerular filtration rate (GFR) categories, and together with kidney failure, these conditions are collectively referred to as CKD, regardless of etiology. In addition, the Kidney Disease: Improving Global Outcomes recommends using equations to estimate GFR (eGFR), which include the routinely obtained variables serum creatinine, age, sex, and race/ethnicity. The use of serum cystatin C, an endogenous filtration marker less influenced than serum creatinine by variations in muscle mass, diet, and tubular secretion, has emerged as an alternative or an adjunct to serum creatinine-based equations, particularly in persons with diabetes, in whom early kidney disease is often characterized by elevated GFR.

Since the late 1990s, new molecular mechanisms have been defined that are helping to explain the development and progression of diabetic kidney disease. Glomerular structural lesions were found to explain 95% of the variability in albumin excretion and 78% of GFR variability. The latter percentage increased to 92% by adding indices of glomerular-tubular junction abnormalities and interstitial expansion to the regression models. Podocyte injury appears to play an essential role in the progression of diabetic nephropathy. In persons with either type 1 or type 2 diabetes, podocyte changes may occur even before the increase in albuminuria, suggesting that diabetes itself may induce podocyte alterations.

Much has also been written about the prognostic implications of CKD. Elevated albuminuria and low GFR are associated with ESRD, fatal and nonfatal CVD, and all-cause mortality. A meta-analysis of 1,024,977 participants (nearly 13% with diabetes) from 30 general population and high-risk cardiovascular cohorts and 13 CKD cohorts indicated that while the absolute risks for all-cause and CVD mortality are higher in the presence of diabetes, the relative risks of ESRD or death by eGFR and albuminuria are similar with or without diabetes. These findings underscore the importance of kidney disease per se as a predictor of important clinical outcomes, regardless of the underlying cause of kidney disease. New biomarkers of diabetic kidney disease appear to have additional prognostic information beyond that provided by albuminuria. These markers include kidney injury molecule 1, liver fatty acid-binding protein, N-acetyl-β-D-glucosaminidase, neutrophil gelatinase-associated lipocalin, β-trace protein, β_2_-microglobulin, and tumor necrosis factor receptors 1 and 2.

Many concepts about risk factors for CKD illustrated in this chapter have not changed since 1995, and where they have, those changes are discussed. In particular, major advances have been made in elucidating the genetic and epigenetic complexity of CKD, which contributed to defining cellular metabolic memory and the understanding of the longlasting effects of strict glycemic control observed in persons with type 1 diabetes or type 2 diabetes.

Improvements in the management of persons with diabetes and CKD have extended the time course from onset of severe albuminuria to ESRD and reduced the occurrence of CVD. In type 1 diabetes, the combined Diabetes Control and Complications Trial (DCCT) and its long-term follow-up, the Epidemiology of Diabetes Interventions and Complications (EDIC) observational study, indicated that intensive early metabolic control reduced the risk of impaired GFR by 50% and of CVD outcomes by 42%, with a specific 57% decrease in myocardial infarction, stroke, or death from CVD, effects that were partly mediated by the reduced incidence of diabetic kidney disease. Among persons with type 2 diabetes, a meta-analysis of randomized controlled trials indicated that more intensive glycemic control (glycosylated hemoglobin [A1c] <7%) was associated with a significant 10% reduction in albuminuria but had no effects on mortality, kidney failure, or other vascular outcomes. The Action to Control Cardiovascular Risk in Diabetes (ACCORD) trial, targeting an A1c level <6.0% in the intensive intervention arm, reported an increased risk of CVD death for intensive versus conventional glycemic control, although it remains unclear whether this effect was related to more hypoglycemic episodes, the use of additional hypoglycemic medicines, or to the target glycemic level itself. Likewise, the modest gains in intermediate outcomes in the intensive treatment arms of the Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation (ADVANCE) and the Veterans Affairs Diabetes (VADT) trial were counterbalanced by a twofold to threefold higher risk of severe hypoglycemia. Together, these trials indicate that glycemic control is extremely useful up to a point, but more aggressive glycemic control may be harmful. Similarly, for blood pressure control, 2014–2015 recommendations by the guideline-writing groups endorse less intensive and more individualized blood pressure targets for diabetes and CKD than in the past. Persons with diabetes and CKD require multidisciplinary management involving a combination of treatments and behavioral adjustments to delay progression of CKD and to prevent the associated complications. The Steno-2 study, a landmark prospective, randomized trial in Denmark, demonstrated that compared with conventional treatment, intensive multifactorial intervention led to 46% lower death rate, 56% less severe albuminuria, 43% lower incidence of diabetic retinopathy, and 47% lower incidence of autonomic neuropathy during the 13.3-year study period.

## Introduction

Important progress has been made since 1995, when the previous edition of Diabetes in America was published, in understanding the course and determinants of diabetic kidney disease and in its treatment (1,2,3,4,5,6,7). Widely accepted criteria for staging of chronic kidney disease (CKD) have been developed, based on the assessment of albuminuria and estimated glomerular filtration rate (eGFR) (7)—estimates of GFR and CKD staging criteria had not yet been developed in 1995. Nevertheless, kidney disease is still a major cause of morbidity and mortality in persons with diabetes, as indicated by the dramatic increase in the number of persons receiving renal replacement therapy since the 1980s. Increased availability of dialysis and transplants and the rising prevalence of diabetes are primarily responsible for this trend. Because kidney disease in diabetes is strongly associated with cardiovascular disease (CVD) and the development of end-stage renal disease (ESRD), the combined cost incurred by CKD and diabetes is associated with a greater percentage of the Medicare budget than that associated with congestive heart failure alone (2). For people with diabetes and kidney disease, the overall Medicare expenditures were approximately $25 billion in 2011 (2).

Projected increases in diabetes prevalence and the increasing frequency of both type 1 and type 2 diabetes in young people threaten to reverse the modest progress achieved with available treatments. Not only is the course of kidney disease in youth-onset type 2 diabetes more aggressive than in type 1 diabetes (4,5), but the Treatment Options for type 2 Diabetes in Adolescents and Youth (TODAY) study suggests it may also be more treatment resistant than kidney disease in adults with type 2 diabetes (6). Although the development of new therapeutic options is essential for improving the management of this complex disease, diabetes prevention may ultimately offer the greatest benefit for stemming the rising tide of diabetic kidney disease.

This chapter has been updated to incorporate the substantial advances made in the past 20 years in the understanding of the pathogenesis, course, and management of CKD in persons with diabetes. It is not a systematic review of the literature but draws from recent publications that did perform such reviews. It also reflects the opinions of the authors about the challenges that may face persons with diabetes and CKD and those who care for them.

## Definition, Measurements, and Classification

CKD attributable to diabetes, referred to as diabetic kidney disease, is defined by reduced kidney function or the presence of kidney damage for at least 3 months, regardless of kidney function (7). Kidney damage is ascertained by increased urinary markers, such as albuminuria, or by abnormal urinary sediment, abnormal imaging studies, or kidney biopsy (7). The clinical diagnosis of diabetic kidney disease is based largely on the finding of elevated excretion of urinary albumin in a person with diabetes in the absence of other kidney disease.

Persons are classified as having elevated albuminuria if the albumin-to-creatinine ratio (ACR) in at least two urine samples collected within 3–6 months is ≥30 mg/g in the absence of clinical or laboratory evidence of urinary tract infection (7). Elevated albuminuria, the earliest marker of diabetic nephropathy, is frequently associated with a progressive decline in kidney function and a high risk for kidney failure and CVD. Although albuminuria is a continuous risk factor, it is often arbitrarily divided into moderately increased albuminuria (ACR 30–299 mg/g)—generally characterized by stable kidney function and a greater risk for higher levels of albuminuria than an ACR <30 mg/g—and severely increased albuminuria (ACR ≥300 mg/g), associated with arterial hypertension and a high risk of kidney failure (Table 22.1) (8). Moderate albuminuria is also referred to as microalbuminuria, and severe albuminuria as macroalbuminuria, overt nephropathy, or clinical proteinuria. Because albuminuria occurs as a continuum, the American Diabetes Association (ADA) recommends simply using the term albuminuria for an ACR ≥30 mg/g (9). Urinary albumin excretion can be determined from 24-hour, overnight, or shorter urine collection periods; however, urinary ACR measured in a first morning void specimen is highly correlated with the 24-hour albumin excretion rate and is therefore an established and recommended way to assess urinary albumin excretion. Differences in methods of urine collection, albumin and creatinine measurements, reporting of results, and lack of standardized reference intervals for ACR often make comparisons between studies difficult.

TABLE 22.1 Albuminuria Categories According to KDIGO Classification

| KDIGO CLASSIFICATION EQUIVALENT
| Normal to Mildly Increased (A1) | Moderately Increased (A2)^*^ | Severely Increased (A3)^†^
AER
μg/min | <20 | 20–200 | >200
mg/24 hours | <30 | 30–300 | >300
ACR
mg/g | <30 | 30–299 | >300
mg/mmol | <3 | 3–30 | >30
PER (mg/24 hours) | <150 | 150–500 | >500
PCR
mg/g | <150 | 150–500 | >500
mg/mmol | <15 | 15–50 | >50
Protein reagent strip | Negative to trace | Trace to + | + or greater

The conversions are rounded; for an exact conversion from mg/g of creatinine to mg/mmol of creatinine, multiply by 0.113. ACR, urinary albumin-to-creatinine ratio; AER, albumin excretion rate; KDIGO, Kidney Disease: Improving Global Outcomes; PCR, protein-to-creatinine ratio; PER, protein excretion rate.

* Relative to young adult level

† Including nephrotic syndrome (albumin excretion usually >2,200 mg/24 hours [ACR >2,220 mg/g; >220 mg/mmol]).

SOURCE: Reference 8, copyright © 2013 Elsevier, reprinted with permission

TABLE 22.2 Kidney Function Categories According to KDIGO Classification

KIDNEY FUNCTION CATEGORY | GFR (ML/MIN/1.73 M^2^) | TERMS
G1 | ≥90 | Normal or high
G2 | 60–89 | Mildly decreased^*^
G3a | 45–59 | Mildly to moderately decreased
G3b | 30–44 | Moderately to severely decreased
G4 | 15–29 | Severely decreased
G5 | <15 | Kidney failure (G5D, if treated by dialysis)

GFR categories G1 and G2 fulfill the criteria for CKD in the presence of markers of kidney damage (e.g., elevated albuminuria). Mildly decreased kidney function (G2) in the absence of other markers is not classified as CKD. CKD, chronic kidney disease; GFR, glomerular filtration rate; KDIGO, Kidney Disease: Improving Global Outcomes.

* Relative to young adult level

SOURCE: Reference 8, copyright © 2013 Elsevier, reprinted with permission

Reduced kidney function is defined by a GFR <60 mL/min/1.73 m^2^, and kidney failure by a GFR <15 mL/min/1.73 m^2^ (Table 22.2) (7,8). Accurate determination of GFR is best achieved by infusing special markers into the bloodstream that are filtered at the glomerulus, but not secreted or reabsorbed by the tubules (e.g., inulin, iothalamate, iohexol, or ^51^Cr-EDTA), and measuring their disappearance from the blood or their appearance in the urine. Because such testing is laborious and expensive to use in large populations, the National Kidney Foundation (NKF) recommends using equations to estimate GFR that include the routinely obtained variables serum creatinine, age, sex, and race/ethnicity. The Modification of Diet in Renal Disease (MDRD) study equation (10) is the most widely used equation for estimating GFR in adults in the office setting and is reasonably accurate when the estimate is <60 mL/min/1.73 m^2^ (11). Precision is lower and bias is higher at higher eGFR values, due in part to declining precision of creatinine measurement at its lower concentrations (12). The newer Chronic Kidney Disease Epidemiology Collaboration equation uses the same variables as the MDRD equation but with reduced bias and similar precision at higher eGFR values, thereby reducing the rate of false-positive results at levels ≥60 mL/min/1.73 m^2^, i.e., the rate of classifying persons to eGFR <60 mL/min/1.73 m^2^ (13). The use of serum cystatin C, an endogenous filtration marker that is less influenced than serum creatinine by variations in muscle mass, diet, and tubular secretion is being explored as an alternative or an adjunct to serum creatinine-based equations, particularly in persons with diabetes, in whom early kidney disease is often characterized by elevated GFR. Regardless of etiology, CKD is classified based on both albuminuria and eGFR categories (Figure 22.1).

In persons with diabetes, CKD may or may not represent diabetic kidney disease, as illustrated in Table 22.3 (14). In those with type 1 diabetes of ≥10 years duration, CKD should be attributed to diabetic kidney disease (14). Among persons with type 2 diabetes in particular, an eye examination is a useful, simple, and noninvasive test for discerning the presence of diabetic kidney disease (15,16). A meta-analysis of 2,012 pooled patients indicated that diabetic retinopathy has a sensitivity of 0.65 (95% confidence interval [CI] 0.62–0.68) and specificity of 0.75 (95% CI 0.73–0.78) for diabetic kidney disease (15). The presence of diabetic retinopathy in those with severe albuminuria is strongly suggestive of diabetic kidney disease, whereas the absence of diabetic retinopathy in those with normal or moderate albuminuria and GFR <60 mL/min/1.73 m^2^ suggests nondiabetic CKD (15,17). Nondiabetic causes of CKD should be considered under the circumstances listed in Table 22.4 (14).

Figure 22.1 illustrates the Kidney Disease: Improving Global Outcomes (KDIGO) CKD classification that reflects prognosis based on the combined measures of GFR and albuminuria (8,18). The risk associations of GFR and albuminuria categories with renal, cardiovascular, and all-cause mortality outcomes are reviewed in the following sections. For screening and management of kidney disease in persons with diabetes, the NKF and the ADA recommend annual ACR screening starting at 5 years duration of type 1 diabetes and at diagnosis of type 2 diabetes (8,19). Serum creatinine measurements and eGFR reporting are recommended at least annually in adults with diabetes, regardless of ACR level.

TABLE 22.3 Likelihood of Chronic Kidney Disease Due to Diabetic Kidney Disease, by Levels of GFR and Albuminuria

GFR (ML/MIN/1.73 M^2^) | CKD STAGE^*^ | ALBUMINURIA
GFR (ML/MIN/1.73 M^2^) | CKD STAGE^*^ | Normal | Moderate | Severe
≥60 | 1 + 2 | At risk^†^ | Possible diabetic KD | Diabetic KD
30–59 | 3 | Unlikely diabetic KD^‡^ | Possible diabetic KD | Diabetic KD
<30 | 4 + 5 | Unlikely diabetic KD^‡^ | Unlikely diabetic KD | Diabetic KD

CKD, chronic kidney disease; GFR, glomerular filtration rate; KD, kidney disease.

* Staging may be confounded by treatment with renin-angiotensin system inhibitors or angiotensin receptor blockers, which reduce albuminuria.

† Kidney biopsy in these persons can show histological evidence of diabetic glomerulopathy.

‡ In the absence of histological evidence, these persons should be considered to have diabetes and CKD and may require further investigation.

SOURCE: Reference 14, copyright © 2007 Elsevier, reprinted with permission

FIGURE 22.1 Classification of Chronic Kidney Disease to Indicate Prognosis Based on the Combined Measures of Albuminuria and Estimated Glomerular Filtration Rate

CKD stages based on both albuminuria and GFR levels are indicated in each cell. Symbols rank adjusted relative risk for five outcomes from a meta-analysis of general population cohorts: all-cause mortality, cardiovascular mortality, kidney failure treated by dialysis and transplantation, acute kidney injury, and progression of kidney disease. CKD, chronic kidney disease; GFR, glomerular filtration rate; KDIGO, Kidney Disease: Improving Global Outcomes.

* Low risk (if no other markers of kidney disease)

† Moderately increased risk

‡ High risk

§ Very high risk

Chart showing C K D classification based on albuminuria categories ranging from normal to severely increased and G F R categories ranging from normal to kidney failure

SOURCE: Reference 8, copyright © 2013 Elsevier, reprinted with permission; and Reference 18

TABLE 22.4 Situations That Prompt Consideration of Nondiabetic Cause(s) of Chronic Kidney Disease

Absence of diabetic retinopathy
Low or rapidly decreasing GFR
Rapidly increasing proteinuria or nephrotic syndrome
Refractory hypertension
Presence of active urinary sediment
Signs or symptoms of other systemic disease
30% reduction in GFR within 2–3 months after initiation of an ACE inhibitor or ARB

ACE, angiotensin-converting enzyme; ARB, angiotensin II receptor blocker; GFR, glomerular filtration rate.

SOURCE: Adapted from Reference 14

## Pathophysiology and Clinical Course

Diabetic kidney disease typically progresses through a number of phases in which albumin or protein excretion increases, and GFR may rise and subsequently falls, frequently culminating in uremia or ESRD (Figure 22.2) (20,21). A diagram of the typical clinical progression of diabetic kidney disease and some of the factors contributing to it is shown in Figure 22.3 (22,23,24,25,26,27,28,29). The clinical manifestations of kidney disease are similar in both type 1 and type 2 diabetes. The major histologic changes of diabetic kidney disease and their relationships with kidney disease progression are discussed in detail in the Morphometry section.

### Albumin Excretion

Urinary albumin excretion is usually normal at the diagnosis of type 1 diabetes, except when ketoacidosis is present. Moderate albuminuria in the early years of diabetes is associated with poor metabolic control but is frequently transitory (21,30,31,32,33,34) and rarely persistent in the first 5 years (35). With treatment, normalization of albuminuria occurs in 58% of persons with type 1 diabetes (36), whereas persistent regression without treatment is observed in 16% (37). Glycosylated hemoglobin (A1c) <8% (<64 mmol/mol), systolic blood pressure <115 mmHg, and low levels of both cholesterol (<198 mg/dL [<5.13 mmol/L]) and triglycerides (<145 mg/dL [<1.64 mmol/L]) are associated with the regression of albuminuria (36). Persons with persistent moderate albuminuria often progress to severe albuminuria (34) over a period of 10–20 years (3%–4% per year) (37,38), with hypertension and proliferative retinopathy also developing with advancing disease. Once overt nephropathy develops, albuminuria regression is less frequent (34,39), and the GFR generally falls at a variable rate (2–20 mL/min/year) (37).

Because the onset of type 2 diabetes is more insidious, poor glycemic control and elevated blood pressure may be present for several years before diagnosis, and therefore, elevated albuminuria is also frequently present at diabetes diagnosis. Approximately 3% of newly diagnosed persons with type 2 diabetes have severe albuminuria (37). The course of urinary protein excretion in type 2 diabetes is more heterogeneous than in persons with type 1 diabetes, in part reflecting a greater heterogeneity of kidney lesions due to the relatively higher prevalence of nondiabetic kidney disease, a consequence of the older age at onset of diabetes (40,41). About 25% of persons with type 2 diabetes have moderate albuminuria after 10 years, and 50% of those who develop moderate albuminuria do so within 20 years of diagnosis (37).

FIGURE 22.2 Outline of the Natural History of Diabetic Kidney Disease in Persons With Type 1 Diabetes

Figure is based on data from 20 men, all of whom developed nephropathy; time between the first examination and follow-up averaged 12±3 years; not all persons had both examinations. Curved lines represent the typical course of GFR (log scale) and UAE; the box in the GFR panel represents the mean±standard deviation of GFR in healthy subjects; the small vertical box in the UAE panel represents the normal range of UAE; and the large horizontal box represents the moderate albuminuria range. GFR, glomerular filtration rate; UAE, urinary albumin excretion.

Line graph showing G F R initially increases in persons with diagnosed diabetes then decreases potentially to E S R D, whereas albumin excretion rises throughout diabetes duration

SOURCE: Reference 21, copyright © 1990 American Diabetes Association, reprinted with permission from The American Diabetes Association

### Glomerular Hemodynamic Function

In healthy adults, the GFR ranges from 90 to 120 mL/min/1.73 m^2^, is stable through mid-adult life, and declines by approximately 1 mL/min per year after age 50 years, with the onset of global kidney sclerosis (42,43,44). The onset of diabetes is associated with hemodynamic changes in the kidney circulation that lead to increased renal plasma flow, glomerular capillary hyperperfusion, and an increased glomerular transcapillary hydraulic pressure gradient (Figures 22.4 and 22.5) (45,46,47,48,49,50,51).

Glomerular capillary hypertension and the ensuing increase in filtration pressure are partly responsible for the elevation of GFR, but various other glomerular and tubular factors also influence the magnitude of the hyperfiltration (52,53,54). The prevalence of hyperfiltration, generally defined as a GFR of at least two standard deviations above the mean GFR in persons with normal glucose tolerance, varies from 40% to 60% in persons with type 1 diabetes and from 7% to 73% in those with type 2 diabetes (26,55,56,57,58,59). The large variations in these estimates are attributed mostly to differences in age, race/ethnicity, glycemic control, duration of diabetes, absence of diet standardization, and methodologies used to measure and report GFR among different populations. In addition, simple single compartment models of plasma disappearance curves will overestimate GFR, and other methods are needed to accurately measure GFR and define its normal range.

Several investigators have reported a relationship between hyperfiltration and the subsequent development of moderate albuminuria and progressive nephropathy (60,61,62), but others have not (24,25,63). Hyperfiltration may also reflect a generalized vascular dysfunction related to diabetes that in turn predisposes to diabetic nephropathy (64,65).

After the initial elevation at onset of diabetes, GFR decreases to a near normal range in response to metabolic control in both type 1 and type 2 diabetes (66,67,68,69), but usually not to levels found in nondiabetic persons (47,69,70,71). In some, this reversal could reflect the initiation of progressive kidney disease, as suggested by the appearance of global glomerular sclerosis and the fall in single-nephron filtration coefficient (72); in others, it could represent a purely functional change in kidney vasomotion associated with improvement in diabetes control or simply the intrinsic variability in GFR in the absence of significant histopathologic changes (73). Distinguishing between these two potential causes of GFR decline requires either observation of GFR over a long period of time to determine whether it plateaus, reverses direction, or continues to decline to pathologic levels, or attention to other biomarkers, including albuminuria.

FIGURE 22.3 Risk Factors For and Clinical Course of Kidney Disease in Diabetes

The thick horizontal arrows represent the reversibility of albuminuria with progressive kidney disease. BMI, body mass index; BP, blood pressure; ESRD, end-stage renal disease; GFR, glomerular filtration rate; IGT, impaired glucose tolerance.

Flow chart showing clinical kidney disease progression throughout diabetes progression

SOURCE: Reference 22

FIGURE 22.4 Mean Glomerular Filtration Rate in Men With Newly Diagnosed Type 1 Diabetes and No Diabetes

Subjects were 31 nondiabetic men and 11 men with newly diagnosed and untreated type 1 diabetes; horizontal lines are mean±standard deviation. The mean GFR was 41% higher in the diabetic subjects than in the nondiabetic subjects. GFR, glomerular filtration rate.

Dot plot showing the distribution of G F R is higher in men with newly diagnosed type 1 diabetes than men without diabetes

SOURCE: Reference 49, copyright © 1971 Informa Healthcare, reprinted with permission

Coincident with the initial elevation of GFR at the diagnosis of diabetes is slightly elevated urinary albumin excretion, although levels in the moderate albuminuria range or above are usually seen only after several years of diabetes (Figure 22.3) (22). The GFR in persons with moderate albuminuria is higher, on average, than in those with normal urinary albumin excretion (74,75). In those with severe albuminuria, it is lower, although in type 2 diabetes, GFR may still be within the normal range (76,77). Cross-sectional data suggest that GFR declines in persons with severe albuminuria, reflecting progressive glomerulosclerosis and loss of filtration surface area. Longitudinal studies confirm this hypothesis (78,79). The absence of albuminuria, however, does not preclude the presence of progressive kidney damage (see the section Incidence of Elevated Urinary Albumin Excretion) (80).

Kidney hemodynamic alterations induced by hyperglycemia and hypertension are believed to cause mechanical stretch and shear stress on endothelial cells and the mesangium, activating complex biochemical pathways that increase extracellular matrix production, hyperglycemia-induced injury, and podocyte damage and loss. These alterations ultimately lead to defects in selective glomerular capillary permeability, albuminuria, protein extravasation into the glomerular mesangium, expansion of mesangial matrix, and glomerulosclerosis (81,82,83,84,85,86,87,88).

### Morphometry

The histologic changes in the kidneys of persons with type 1 diabetes and CKD are well described, typically homogenous, and predict development of elevated albuminuria, ESRD, and cardiovascular death (89,90,91). On the other hand, the kidney lesions underlying CKD in type 2 diabetes are more heterogeneous (92,93). Whether the natural history of CKD in diabetes varies by histologic lesion remains unknown, although longitudinal studies suggest a relationship between renal lesions and GFR decline (94,95). This section reviews the morphometric characteristics of diabetic kidney disease.

FIGURE 22.5 Glomerular Filtration Rate and Renal Plasma Flow in Individuals With Type 2 Diabetes and Without Diabetes

GFR and effective renal plasma flow were measured in 110 persons with type 2 diabetes and 32 nondiabetic subjects; mean values are shown for each group. Mean GFR averaged 23% higher and renal plasma flow 13% higher in the diabetic subjects. GFR, glomerular filtration rate.

Dot plots showing the distribution of G F R and the effective renal plasma flow are higher in persons with type 2 diabetes than persons without diabetes

SOURCE: Reference 51, copyright © 1992 Elsevier, reprinted with permission

To appear in the urine, albumin must cross each layer of the glomerular filtration barrier consisting of the endothelial surface layer, fenestrated endothelial cells, glomerular basement membrane, and the glomerular epithelial cells or podocytes. Elevated albuminuria is an early clinical indicator of diabetic kidney disease, reflecting at the glomerular level the destruction of the endothelial surface layer (96,97,98,99), reduction in size and density of endothelial cell fenestrations (100,101,102), and thickening of the basement membranes. Subsequent mesangial expansion and podocyte injury and detachment further increase albuminuria, decreasing the available capillary filtration surface and leading to glomerulosclerosis. In addition to the glomerular morphologic lesions, diabetes progressively affects the kidney tubules, interstitium, and arterioles.

One of the earliest structural abnormalities in diabetes is thickening of the glomerular and tubular basement membranes due to excessive deposition of normal extracellular matrix components (85,93,103,104). Glomerular basement membrane thickening strongly correlates with albuminuria and less with GFR, suggesting that it is a good indicator of early diabetic kidney disease. This alteration is followed by an increase in the mesangial volume per glomerulus (fractional mesangial volume), primarily through expansion of the mesangial matrix, with the increase in the volume fraction of the mesangial cellular component playing a secondary role (105). The fractional mesangial volume is correlated inversely with GFR, and positively with ACR and hypertension (57,104,106), and is therefore a strong predictor of progressive kidney dysfunction (Figure 22.6) (107). Virtually all persons with type 1 diabetes and advanced kidney disease have markedly thickened glomerular basement membrane and diffuse mesangial expansion. About 25% of persons with >10 years of diabetes duration present with Kimmelstiel-Wilson nodules, which are rounded, paucicellular, lamellated accumulations of mesangial matrix at the periphery of the glomerulus (108,109). Kimmelstiel-Wilson lesions correlate with longer diabetes duration, higher serum creatinine, and more severe diabetic retinopathy (110). Mesangial expansion changes the architecture of the glomerular tuft, restricts the cellular component, distorts and occludes glomerular capillaries, decreasing the available capillary filtration surface and contributing to the decline in kidney function. Glomerular hypertrophy may compensate for the loss of filtration surface area, providing a means by which GFR is maintained in progressive kidney disease (111).

FIGURE 22.6 Glomerular Basement Membrane and Fractional Mesangial Volume by Albuminuria in Persons With Type 1 Diabetes

GBM width and Vv(Mes/glom) in 88 normoalbuminuric (NA), 17 moderately albuminuric (MA), and 19 proteinuric (P) persons with type 1 diabetes. Normoalbuminuria is defined as AER <20 µg/min, moderate albuminuria as AER 20–200 µg/min, proteinuria as AER ≥200 µg/min on at least two of three measurements. The shaded bars represent mean±2 standard deviations in a group of 76 age-matched normal control subjects. AER, albumin excretion rate; GBM, glomerular basement membrane; Vv(Mes/glom), fractional mesangial volume.

Dot plot showing glomerular basement membrane width and fractional mesangial volume lower in normoalbuminuric persons than those with moderate albuminuria and proteinuria

SOURCE: Reference 107, copyright © 2002 American Diabetes Association, reprinted with permission from The American Diabetes Association

Podocyte injury appears to play an essential role in the progression of diabetic nephropathy. The podocyte with its extended foot processes, provides structural support for the glomerular capillaries, as well as hydraulic resistance, and prevents the escape of proteins into the urinary space (112). With glomerular hypertrophy, the podocytes, which have a limited proliferative potential (113,114,115,116), stretch their foot processes more broadly to maintain coverage of the expanded glomerular basement membrane, a compensatory mechanism believed to influence their functional integrity (117). In addition, glomerular endothelial cell dysfunction, which precedes podocyte injury (100), appears to contribute to the latter through several mechanisms, including protein overload and toxicity at the podocyte level due to saturation of clearance mechanisms (118), increased shear stress (97), decreased endothelial nitric oxide synthase (eNOS) expression and activity (119,120), and production of cytokines, proteoglycans, and growth factors (100). Podocytes are known to absorb excess albumin arriving in the surrounding urinary space, and this increased workload may initiate inflammatory signaling and contribute to changes in podocyte-associated molecules and foot process effacement (121,122). Sustained mechanical stress and glomerular hypertension may ultimately lead to podocyte detachment and loss in the urine, leaving areas of bare glomerular basement membrane that further enhance loss of protein (Figure 22.7) (102). These denuded areas may initiate glomerular-tubular junction abnormalities and focal or global glomerular sclerosis (103). In persons with either type 1 (123) or type 2 diabetes (102,124), podocyte changes may occur even before the increase in ACR, suggesting that diabetes itself may induce podocyte alterations. In a study of persons with type 2 diabetes, moderate albuminuria was associated with 20% and severe albuminuria with 40% podocyte loss relative to normal albuminuria (117). Moreover, individuals with moderate albuminuria had a 35% decline in the number of podocytes per glomerulus, and half of them progressed to severe albuminuria during 4 years of follow-up (72). Similarly, a lower number of podocytes and changes in the shape of the remaining podocytes were found in persons with type 2 diabetes and elevated ACR when compared with those with normal ACR and similar fractional mesangial volume, indicating that changes in podocyte structure and density occur early during diabetic nephropathy and contribute to albuminuria. Other cross-sectional and experimental studies have reported similar findings (115,125). Some data suggest a repair mechanism via recruitment of parietal epithelial cells that is overwhelmed when podocyte loss exceeds a modest threshold (126,127,128). Consequently, significant damage to the podocytes is a potential starting point for irreversible glomerular injury in diabetic kidney disease.

FIGURE 22.7 Peripheral Glomerular Capillaries From Pima Indians With Type 2 Diabetes

Transmission electron microscopy, × 11,280. (A) Intact podocyte foot processes (P) attached to glomerular basement membrane (GBM). (B) Local podocyte detachment (PD) and denuded GBM. CL, capillary lumen; E, capillary endothelium.

Picture showing local podocyte detachment in peripheral glomerular capillaries in a Pima Indian with type 2 diabetes

SOURCE: Original figure provided by R. G. Nelson.

Interstitial expansion, in contrast with mesangial expansion, primarily involves a cellular component represented by T lymphocytes and macrophages that infiltrate the interstitium, with subsequent fibrosis and declining GFR (129,130). Efferent and afferent arteriolar hyalinosis, consisting of intramural accumulations of plasma proteins and lipids within kidney arterioles, may occur within a few years of diabetes onset (104,131,132). Although afferent arteriolar hyalinosis is less specific to diabetic nephropathy, both lesions are associated with increased albumin excretion and progression of kidney disease. Similar exudative lesions may occur in the glomerular capillaries (hyalinosis), Bowman’s capsule (capsular drops) (133,134), or proximal convoluted tubules and are generally associated with advanced diabetic nephropathy (104).

Abnormalities of the glomerular-tubular junction, typically associated with proteinuria (135), include focal adhesions, atrophic tubules, or atubular glomeruli.

These lesions further contribute to the loss of kidney function in diabetes. Advanced diabetic kidney disease is characterized by a marked reduction in the number of functioning glomeruli and further compensatory enlargement of those that remain functional. This stage is associated with markedly reduced GFR.

The intra- and extraglomerular morphologic changes described in this section progress at variable rates. Nonetheless, in one study, glomerular structural lesions explained 95% of the variability in albumin excretion and 78% of GFR variability (107,135). The latter percentage increased to 92% by adding indices of glomerular-tubular junction abnormalities and interstitial expansion to the regression models (135).

Albuminuria, however, is neither a sensitive nor specific early biomarker of progression to ESRD, and the absence of albuminuria does not exclude the presence of relatively advanced diabetic renal lesions and progressive kidney damage (136,137,138,139,140,141,142,143,144). New biomarkers of diabetic kidney disease appear to have additional prognostic information beyond that provided by albuminuria. These markers include kidney injury molecule 1 (KIM-1), liver fatty acid-binding protein (L-FABP), N-acetyl-β-D-glucosaminidase (NAG), neutrophil gelatinase-associated lipocalin (NGAL) (145,146,147,148,149,150,151,152,153,154,155,156,157,158,159,160,161), β-trace protein, β_2_-microglobulin (162,163,164), and tumor necrosis factor receptors 1 and 2 (165,166,167,168,169,170,171,172). Tumor necrosis factor-alpha receptor 1 and receptor 2 consistently enhance the discrimination of the survival models for ESRD beyond that achievable by the clinically recognized risk factors in persons with type 1 or type 2 diabetes (165,166,167,168,169,170,171,172). Evaluation of other biomarkers in relation to diabetic kidney disease often shows conflicting results (145,146,147,148,149,150,151,152,153,154,155,156,157,158,159,160,161). This may be due to differences in study design, inclusion of persons without diabetes, use of surrogate or composite outcomes, or incomplete covariate adjustment in risk models (161).

### Selective Glomerular Permeability

The glomerular capillary wall serves as a filter that discriminates among molecules on the basis of size, electrical charge, and configuration. Studies of glomerular filtrate collected by micropuncture or narrow size fractioning of exogenous polymers, such as dextran, indicate that albuminuria is primarily the result of impairment of the electrostatic barrier within the glomerulus, consequent to a decrease in endothelial cell glycocalyx (173,174) and heparan sulfate content of the glomerular basement membrane (175,176), and by changes in size selectivity across the glomerular capillary wall (Figure 22.8) (56,177,178,179,180,181,182,183,184,185,186,187,188,189,190,191,192,193).

A comparison of the mean dextran sieving profiles in 43 initially microalbuminuric Pima Indians with type 2 diabetes, who were followed for up to 8 years, showed no difference in the size selectivity of the glomerular filtration barrier between participants with moderate albuminuria and long-term normoalbuminuric control subjects (194). However, participants with severe albuminuria after 4 years of follow-up had a significantly higher fractional clearance of the large-radius test molecules than normoalbuminuric controls, with a reduction at the low-radius end, as shown in Figure 22.9. When the macromolecular shunt was analyzed as a function of albumin excretion, an abrupt transition was apparent at an ACR of approximately 3,000 mg/g (Figure 22.10), whereas the contribution of the shunt in the moderate albuminuria range was very small. These data suggest that permselectivity defects in the glomerular filtration barrier have little or no role in the development of moderate albuminuria. By contrast, a primary contributor to severe albuminuria is the shunt resulting from the presence of large pores within the glomerular capillary wall through which plasma proteins can easily pass (195,196,197,198). Morphometric data in participants with severe albuminuria identified a significant correlation between the shunt magnitude and podocyte foot process width (p=0.027) (Figure 22.11) (194), which was not discernible in participants with moderate albuminuria. A similar size-selectivity defect has been reported in type 1 diabetes (190,195). These findings are consistent with the view that permselectivity defects responsible for increased albumin excretion may be focal and likely due to podocyte foot process effacement and simplification and, possibly, to defective intercellular junctions (199).

With the application in the late 1990s of multiphoton fluorescence techniques to kidney research, direct imaging of the structure and function of living kidney tissue was possible (200). In some studies, this technique revealed what appeared to be a much higher albumin glomerular sieving coefficient than was calculated or measured by micropuncture, prompting some investigators to propose alternative explanations for the facilitated urinary clearance of albumin in diabetic kidney disease (200,201), including the idea that elevated albuminuria is the result of a proximal tubular cell dysfunction in retrieving and degrading albumin and does not reflect an alteration in glomerular permselectivity (201,202). Later studies using improved imaging techniques do not support this concept and confirm that glomerular filtration barrier permeability to macromolecules is largely restricted to areas of podocyte damage (203,204,205).

FIGURE 22.8 Fractional Dextran Clearance Profile in Pima Indians With and Without Type 2 Diabetes

The figure compares the fractional dextran clearance profile in persons with type 2 diabetes and those with normal glucose tolerance. Fractional dextran clearances in subjects with diabetes were uniformly elevated over the entire range of molecular radii tested. The elevation was most marked at the large radius end of the profile, with statistically significant differences (p<0.05) for dextrans of ≥48 Å radius.

Line graph showing the fractional dextran clearance decreases with increasing dextran radius similarly for people with and without diabetes

SOURCE: Reference 56

FIGURE 22.9 Dextran Sieving Curves in Pima Indians With Type 2 Diabetes

Sieving coefficient was measured in 31 persons with diabetes and severe albuminuria at 48 months follow-up (▵) and 11 diabetic controls with long-term normoalbuminuria (○). Lines are best-fit splines. A significant elevation of the sieving curve at its large-radius end and a tendency toward depression at the low-radius end is found in persons with severe albuminuria. Error bars represent one standard deviation. ESR, Einstein-Stokes radius.

* p<0.05

Line graph showing people with albuminuria, compared to those with normal albumin, have a higher dextran sieving coefficient among large-radius molecules but not at the low-radius end

SOURCE: Reference 194, copyright © 2000 American Society of Nephrology, reprinted with permission

FIGURE 22.10 Graph of the Shunt Magnitude as a Function of Albuminuria

The shunt magnitude parameter (ω_0_) as a function of albuminuria, as reflected by (A) the fractional clearance of albumin and (B) the urinary albumin-to-creatinine ratio (A/C)—for the combined moderate (○) and severe (▴) albuminuria groups (n=73). The shaded bar represents the 25th–75th percentiles of the ω_0_ distribution of normoalbuminuric control subjects.

Line graph showing an increase in shunt magnitude at higher levels of fractional clearance of albumin and albumin-to-creatinine ratio

SOURCE: Reference 194, copyright © 2000 American Society of Nephrology, reprinted with permission

FIGURE 22.11 Relationship Between Shunt Magnitude and Mean Podocyte Foot Process Width

Shunt magnitude (ω_0_) and mean foot process width in 10 persons with severe albuminuria who had kidney biopsies.

Line graph showing that shunt magnitude increases at higher levels of foot process width

SOURCE: Reference 194, copyright © 2000 American Society of Nephrology, reprinted with permission

## Elevated Urinary Albumin Excretion

As noted earlier in this chapter, urinary albumin excretion is often increased at the diagnosis of both types of diabetes but frequently returns to normal with the institution of glycemic control (21,30,31,32). Persistent albuminuria at the onset of type 2 diabetes, however, may reflect diabetes that has remained undiagnosed for years (32) or the presence of kidney disease unrelated to diabetes, since other kidney diseases are common at the ages when type 2 diabetes typically develops. On the other hand, elevated urinary albumin excretion is found in persons with impaired glucose tolerance (206,207,208), raising the possibility that hyperglycemia, even at levels below those diagnostic of diabetes, is sometimes associated with kidney abnormalities.

### Prevalence of Elevated Urinary Albumin Excretion

The prevalence of elevated albuminuria (ACR ≥30 mg/g) in the U.S. adult population with self-reported diabetes was 35.9%, 32.6%, and 29.3% based on a one-time random spot urine measurement collected for the National Health and Nutrition Examination Surveys (NHANES) 1988–1994, 1999–2004, and 2007–2012, respectively (Table 22.5) (1). When measured in a first morning void sample, the prevalence of ACR ≥30 mg/g in NHANES 2009–2010 participants with self-reported diabetes was 15.7% (95% CI 12.3%–19.0%) (209) (prevalences of moderate albuminuria 11.9%, 95% CI 9.7%–14.4%, and severe albuminuria 3.8%, 95% CI 2.2%–6.4%, were computed in a new analysis for Diabetes in America, 3rd edition). These estimates were significantly lower than the 24.1% prevalence (95% CI 19.8%–28.2%) of ACR ≥30 mg/g obtained from a random spot urine in the same population (prevalences of moderate albuminuria 19.3%, 95% CI 16.0%–23.1%, and severe albuminuria 4.8%, 95% CI 3.1%–7.4%, were computed in a new analysis for Diabetes in America). Prevalence of elevated ACR was significantly lower in the NHANES population without diabetes (6.2%, 95% CI 4.9%–7.5%, in random urine samples and 3.7%, 95% CI 2.9%–4.5%, in first morning voids) (209). As mentioned in the Definition, Measurements, and Classification section, ACR measurement in first morning urine is a more reliable indicator of albumin excretion, since it correlates better with the 24-hour albumin excretion rate (AER) than the ACR measured in random spot urine. This suggests that ACR measurements based on single random spot urine specimens—the standard measurement in the NHANES—likely overestimate the frequency of elevated ACR in the general population (210,211,212).

Because of the high intraindividual variation of ACR, both NKF and ADA guidelines (8,9,19) recommend confirmation of elevated albuminuria in a repeat measurement—either first morning void or random urine sample. The prevalence of persistent albuminuria, defined as elevated ACR in two consecutive random urine measurements within 2 weeks, was 15.9% in adults with diabetes (defined by A1c ≥6.5% [≥48 mmol/mol] or use of glucose-lowering medicines) in the NHANES 2009–2014, lower than the 20.8% prevalence in the NHANES III (1988–1994) (age, sex, and race/ethnicity adjusted prevalence ratio 0.76, 95% CI 0.65–0.89) (213). This overall change was due to lower albuminuria prevalence in adults age <65 years and non-Hispanic whites over time. By contrast, the prevalence of low eGFR increased during the same time in the overall population with diabetes. Trends in persistent albuminuria and eGFR <60 mL/min/1.73 m^2^ in the general U.S. population with diabetes are shown in Table 22.6 by age group (213). The prevalence of low eGFR in the U.S. population with diabetes has increased over time among non-Hispanic white and black adults (Table 22.7) (213).

By design, the NHANES does not differentiate the type of diabetes, and results in the adult population with self-reported diabetes may largely reflect the experience of persons with type 2 diabetes. In a new analysis of NHANES 1999–2010 data conducted for Diabetes in America, the prevalence of CKD by type of diabetes was estimated using a published algorithm (214) to define persons with type 1 diabetes (Table 22.8). Results showed a higher prevalence of CKD in those with type 2 diabetes than in those with type 1 diabetes, regardless of sex, and a higher prevalence in non-Hispanic blacks than in non-Hispanic whites. CKD was also more frequent in persons with hypertension or CVD, regardless of type of diabetes.

In the Pittsburgh Epidemiology of Diabetes Complications (EDC) study, the prevalences of both moderate and severe albuminuria were higher in the 210 men than the 180 women diagnosed with type 1 diabetes between 1950 and 1964 (moderate albuminuria prevalence: 75% in men vs. 53.8% in women, p=0.001; severe albuminuria prevalence: 53.1% in men vs. 32.0% in women, p=0.002) (Figure 22.12) (215). In the cohort with diabetes onset between 1965 and 1980 (260 men and 283 women), sex differences in some CKD risk factors diminished, as did the differences in albuminuria prevalence (moderate albuminuria: 42.6% in men vs. 41.9% in women, p=0.9; severe albuminuria: 18.1% in men vs. 22.4% in women, p=0.3) (Figure 22.12). The prevalence of albuminuria in a population-based study of 706 insulin-treated subjects in Wisconsin with diabetes onset at age <30 years, presumably mostly persons with type 1 diabetes, is shown in Table 22.9 (216). The overall prevalence was 21.2% for moderate albuminuria (≥0.03–0.29 g albumin/L) and 21.1% for severe albuminuria (≥0.30 g albumin/L). In the Finnish Diabetic Nephropathy (FinnDiane) study (217), moderate albuminuria was present in 12% and severe albuminuria in 14% of adult clinic-based patients with type 1 diabetes, lower than the prevalences of 23% (31–299 mg albumin/24 hours) and 19% (≥300 mg albumin/24 hours) found in 876 clinic-based patients in Denmark (218). Figure 22.13 shows the prevalence of albuminuria in these clinic-based patients in Denmark as a function of the duration of diabetes. The prevalence data reported in the studies above are higher than those reported in a nationwide cohort of Norwegians with type 1 diabetes (19% for moderate albuminuria, 15–200 mg/min; 7.8% for severe albuminuria, >200 mg/min) (219), in an observational study from the Swedish National Registry (12.2% for moderate albuminuria; 7.4% for severe albumin-uria) (220), or in the type 1 diabetes population in Germany (3.3% for moderate albuminuria, ACR ≥2.5 mg/mmol; 0.2% for severe albuminuria, ACR ≥35 mg/mmol) (221). The differences are likely due to the shorter duration of diabetes and better metabolic control in the latter studies, which included observations after the year 2002.

TABLE 22.5 Prevalence of Chronic Kidney Disease in Adults Age ≥20 Years, by Age, Sex, Race/Ethnicity, and Risk Factor Categories, U.S., 1988–1994, 1999–2004, and 2007–2012

CHARACTERISTICS | ALL CKD | | | EGFR <60 ML/MIN/1.73 M^2^ | | | ACR ≥30 MG/G
CHARACTERISTICS | 1988–1994 | 1999–2004 | 2007–2012 | 1988–1994 | 1999–2004 | 2007–2012 | 1988–1994 | 1999–2004 | 2007–2012
All | 12.0 | 14.0 | 13.6 | 4.9 | 6.2 | 6.5 | 8.8 | 9.8 | 9.2
Age (years)
20–39 | 5.1 | 5.9 | 5.7 | 0.1 | 0.3 | 0.2 | 5.0 | 5.8 | 5.5
40–59 | 8.4 | 9.8 | 8.9 | 1.3 | 2.0 | 2.3 | 7.5 | 8.4 | 7.2
≥60 | 32.2 | 37.5 | 33.2 | 19.1 | 25.1 | 22.7 | 18.0 | 20.1 | 17.7
Sex
Men | 10.2 | 12.3 | 12.1 | 4.1 | 5.0 | 5.4 | 7.4 | 9.2 | 8.7
Women | 14.2 | 15.7 | 15.1 | 5.6 | 7.2 | 7.6 | 10.2 | 10.3 | 9.6
Race/ethnicity
Non-Hispanic white | 12.3 | 14.0 | 13.9 | 5.5 | 7.0 | 7.6 | 8.2 | 8.9 | 8.4
Non-Hispanic black | 14.5 | 14.9 | 15.9 | 4.1 | 5.0 | 6.2 | 12.7 | 12.4 | 12.3
Other | 10.5 | 13.5 | 11.7 | 2.2 | 3.4 | 3.1 | 9.2 | 11.7 | 10.1
Risk factor
Diabetes | 43.1 | 42.0 | 39.2 | 15.6 | 17.0 | 19.6 | 36.3 | 33.3 | 28.6
Self-reported diabetes | 42.7 | 42.2 | 40.4 | 16.4 | 18.5 | 21.1 | 35.9 | 32.6 | 29.3
Hypertension | 33.3 | 32.7 | 31.0 | 15.3 | 17.1 | 17.1 | 23.4 | 21.3 | 19.8
Self-reported hypertension | 25.3 | 27.2 | 26.0 | 12.9 | 15.8 | 15.2 | 17.1 | 16.4 | 16.2
Cardiovascular disease | 25.4 | 40.0 | 39.5 | 14.5 | 27.3 | 26.8 | 16.6 | 23.0 | 23.8
Obesity (BMI ≥30 kg/m^2^) | 16.6 | 16.8 | 16.6 | 6.2 | 6.4 | 7.3 | 12.3 | 12.6 | 11.5

Data were derived from participants in the National Health and Nutrition Examination Surveys 1988–1994, 1999–2004, and 2007–2012. eGFR and ACR are single-sample estimates; eGFR was calculated using the CKD-EPI equation. Diabetes is defined as A1c >7%, self-reported, or currently taking glucose-lowering medications. Hypertension is defined as blood pressure ≥130/≥80 mmHg for those with diabetes or CKD, otherwise blood pressure ≥140/≥90 mmHg or taking medication for hypertension. Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; ACR, urinary albumin-to-creatinine ratio; BMI, body mass index; CKD, chronic kidney disease; CKD-EPI, Chronic Kidney Disease Epidemiology Collaboration equation; eGFR, estimated glomerular filtration rate.

SOURCE: Reference 1

TABLE 22.6 Prevalence of Albuminuria and Decreased Glomerular Filtration Rate in Adults Age ≥20 Years With Diabetes, by Age and Time Period, U.S., 1988–2014

AGE (YEARS), TIME PERIOD | ALBUMINURIA | | | | DECREASED EGFR
AGE (YEARS), TIME PERIOD | N^*^ | Prevalence (95% CI) | | P for Trend | N^*^ | Prevalence (95% CI) | | P for Trend
AGE (YEARS), TIME PERIOD | N^*^ | Unadjusted (%) | Adjusted Ratio^†^ | P for Trend | N^*^ | Unadjusted (%) | Adjusted Ratio^†^ | P for Trend
≥20
1988–1994 | 534 | 20.8 (16.3–25.3) | 1 [Reference] | | 214 | 9.2 (6.2–12.2) | 1 [Reference]
1999–2004 | 531 | 18.9 (15.3–22.4) | 0.93 (0.79–1.06) | <0.001 | 273 | 11.6 (8.5–14.6) | 1.33 (1.09–1.63) | <0.001
2005–2008 | 447 | 17.9 (14.0–21.9) | 0.86 (0.75–1.01) | | 242 | 11.8 (8.4–15.1) | 1.38 (1.09–1.75)
2009–2014 | 645 | 15.9 (12.7–19.0) | 0.76 (0.65–0.89) | | 450 | 14.1 (11.3–17.0) | 1.61 (1.33–1.95)
20–64
1988–1994 | 256 | 19.5 (13.5–25.4) | 1 [Reference] | | 40 | 2.9 (0–5.9) | 1 [Reference]
1999–2004 | 244 | 17.6 (12.9–22.3) | 0.89 (0.72–1.11) | 0.001 | 43 | 3.9 (1.3–6.5) | 1.45 (0.80–2.61) | 0.15
2005–2008 | 224 | 15.7 (10.5–20.8) | 0.80 (0.64–0.99) | | 53 | 4.3 (1.8–6.9) | 1.62 (0.89–2.94)
2009–2014 | 327 | 14.0 (10.1–18.0) | 0.70 (0.57–0.87) | | 95 | 5.5 (2.9–8.2) | 1.95 (1.12–3.39)
≥65
1988–1994 | 278 | 22.1 (15.9–28.4) | 1 [Reference] | | 174 | 19.3 (13.4–25.3) | 1 [Reference]
1999–2004 | 287 | 20.7 (15.9–25.5) | 0.94 (0.77–1.15) | 0.15 | 230 | 24.6 (18.4–30.9) | 1.26 (1.04–1.54) | <0.001
2005–2008 | 223 | 21.9 (17.0–26.8) | 0.96 (0.80–1.16) | | 189 | 24.4 (18.0–30.9) | 1.28 (0.99–1.64)
2009–2014 | 318 | 19.2 (14.9–23.4) | 0.84 (0.68–1.03) | | 355 | 28.9 (22.9–34.9) | 1.53 (1.27–1.85)

Albuminuria is defined as persistent albumin-to-creatinine ratio ≥30 mg/g; decreased estimated glomerular filtration rate (eGFR) is defined as persistently <60 mL/min/1.73 m^2^. Diabetes is defined by A1c ≥6.5% or use of glucose-lowering medicines. Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CI, confidence interval; GFR, glomerular filtration rate.

* Unweighted number of National Health and Nutrition Examination Survey participants with diabetes

† Adjusted for age, sex, and race/ethnicity.

SOURCE: Reference 213

A cross-sectional, clinic-based study of 24,151 patients from 33 countries worldwide with type 2 diabetes, mean diabetes duration of 8 years, and without previously known albuminuria found overall prevalences of moderate and severe albuminuria of 39% and 10%, respectively (222). Compared with whites, who had the lowest prevalence of albuminuria, Asian and Hispanic patients had nearly twice the odds of albuminuria (adjusted odds ratios [OR] 1.8, 95% CI 1.59–1.97, and OR 1.7, 95% CI 1.47–1.94, respectively). African patients were younger and had shorter duration of diabetes than other racial/ethnic groups, but the odds of albuminuria were 1.5-fold higher than in whites (95% CI 1.20–1.83), who had the lowest A1c levels and the highest frequency of antihypertensive, lipid-lowering, and anticoagulant or antiplatelet usage. Among Pima Indians with type 2 diabetes (207), 26% had moderate albuminuria (ACR 30–299 mg/g) and 21% had severe albuminuria (ACR ≥300 mg/g), and in the population on the Western Pacific island of Nauru (208), 41% had moderate albuminuria (ACR 30–299 mg/mL) and 31% had severe albuminuria (ACR ≥300 mg/mL). Figure 22.14 shows the prevalence of moderate and severe albuminuria in Pima Indians according to duration of diabetes (207). Although different methods and definitions of urinary albumin excretion were employed in these studies, other factors must be invoked to explain the large differences in the prevalence of elevated urinary albumin excretion in these different groups. Additional contributing factors may include racial/ethnic differences, as well as differences in duration of diabetes, blood pressure and metabolic control, diet, and perhaps genetic susceptibility to diabetic kidney disease.

TABLE 22.7 Prevalence of Albuminuria and Decreased Glomerular Filtration Rate in Adults Age ≥20 Years With Diabetes, by Race/Ethnicity and Time Period, U.S., 1988–2014

RACE/ETHNICITY, TIME PERIOD | N^*^ | PREVALENCE (95% CI)
RACE/ETHNICITY, TIME PERIOD | N^*^ | Unadjusted (%) | Adjusted Ratlo^†^ | P for Trend
Albuminuria
Non-Hispanic white
1988–1994 | 179 | 21.2 (14.9–27.5) | 1 [Reference] | 0.001
1999–2004 | 179 | 17.1 (12.8–21.4) | 0.81 (0.65–0.99)
2005–2008 | 169 | 17.4 (12.8–22.1) | 0.82 (0.68–1.00)
2009–2014 | 204 | 14.2 (9.9–18.5) | 0.67 (0.53–0.85)
Non-Hispanic black
1988–1994 | 153 | 19.4 (14.0–24.9) | 1 [Reference] | 0.50
1999–2004 | 127 | 21.1 (15.6–26.6) | 1.09 (0.89–1.33)
2005–2008 | 131 | 19.2 (13.7–24.8) | 1.00 (0.81–1.22)
2009–2014 | 173 | 18.3 (13.7–22.9) | 0.93 (0.78–1.11)
Mexican American
1988–1994 | 184 | 20.4 (14.2–26.6) | 1 [Reference] | 0.95
1999–2004 | 179 | 20.9 (15.4–26.3) | 1.03 (0.85–1.25)
2005–2008 | 95 | 21.0 (14.2–27.8) | 1.01 (0.79–1.30)
2009–2014 | 131 | 21.0 (15.1–27.0) | 1.00 (0.80–1.24)
Decreased eGFR
Non-Hispanic white
1988–1994 | 102 | 9.8 (5.5–14.0) | 1 [Reference] | <0.001
1999–2004 | 138 | 12.9 (8.7–17.1) | 1.36 (1.06–1.73)
2005–2008 | 123 | 13.3 (8.1–18.6) | 1.42 (1.05–1.92)
2009–2014 | 206 | 16.1 (12.1–20.0) | 1.65 (1.32–2.06)
Non-Hispanic black
1988–1994 | 63 | 8.2 (4.6–11.8) | 1 [Reference] | <0.001
1999–2004 | 63 | 9.6 (5.3–14.0) | 1.18 (0.89–1.56)
2005–2008 | 70 | 11.5 (6.1–17.0) | 1.39 (1.01–1.92)
2009–2014 | 120 | 13.0 (9.0–17.1) | 1.55 (1.20–2.01)
Mexican American
1988–1994 | 43 | 4.6 (1.5–7.7) | 1 [Reference] | 0.14
1999–2004 | 56 | 5.3 (2.3–8.3) | 1.11 (0.66–1.86)
2005–2008 | 31 | 5.8 (1.8–9.8) | 1.21 (0.67–2.21)
2009–2014 | 50 | 7.2 (3.0–11.4) | 1.42 (0.88–2.31)

Albuminuria is defined by persistent urine albumin-to-creatinine ratio ≥30 mg/g; decreased estimated glomerular filtration rate (eGFR) is defined as persistently <60 mL/min/1.73 m^2^. For albuminuria, p=0.007 for race/ethnicity × time interaction; for eGFR, p=0.99 for race/ethnicity × time interaction. CI, confidence interval; CKD, chronic kidney disease.

* Unweighted number of National Health and Nutrition Examination Survey participants with diabetes and CKD

† Adjusted for age, sex, and race/ethnicity.

SOURCE: Reference 213, reproduced with permission, copyright © 2016 American Medical Association. All rights reserved.

TABLE 22.8 Crude Prevalence of Chronic Kidney Disease Stages 1–5 in Adults Age ≥20 Years, by Type of Diabetes, U.S., 1999–2010

CHARACTERISTICS | PERCENT (STANDARD ERROR)
CHARACTERISTICS | Type 1 Diabetes (N=68) | Type 2 Diabetes (N=3,933)
All | 27.6 (7.15) | 39.4 (0.88)
Age (years)
20–44 | 13.9 (5.68)^2^ | 29.6 (2.73)
45–64 | 47.0 (13.43) | 29.1 (1.38)
≥65 | 65.3 (29.1)^2^ | 54.8 (1.33)
Sex
Men | 27.3 (11.46)^2^ | 39.1 (1.39)
Women | 28.1 (7.42) | 39.6 (1.35)
Race/ethnicity
Non-Hispanic white | 24.4 (8.56)^1^ | 38.7 (1.09)
Non-Hispanic black | 47.2 (12.54) | 40.7 (1.94)
Mexican American | ^3^ | 37.7 (1.75)
Cardiovascular disease
Yes | 57.0 (27.07)^2^ | 53.3 (2.05)
No | 23.7 (6.07) | 34.4 (1.00)
Hypertension
Yes | 48.0 (9.87) | 44.9 (1.03)
No | ^3^ | 24.7 (1.60)

Type 1 diabetes includes individuals with self-reported diabetes whose age of diagnosis was <30 years, who currently use insulin, and who began insulin therapy within 1 year of diabetes diagnosis. Type 2 diabetes includes individuals with self-reported diabetes who are not defined as having type 1 diabetes or those with undiagnosed diabetes based on A1c ≥6.5% or fasting plasma glucose ≥126 mg/dL. Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin.

1 Relative standard error >30%–40%

2 Relative standard error >40%–50%

3 Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 1999–2010

### Incidence of Elevated Urinary Albumin Excretion

Moderate albuminuria predicts the development of severe albuminuria in persons with type 1 (223,224,225,226,227) or type 2 diabetes (228,229,230,231). In type 1 diabetes, persistent albuminuria rarely develops in the first 10 years after diagnosis (232,233,234). The rate of progression to severe albuminuria is highest between 10 and 20 years duration of diabetes, and subsequently, the incidence rate declines (130,219,235). In the Diabetes Control and Complications Trial (DCCT), the cumulative incidence of persistent moderate albuminuria was 14%, 33%, and 38% at 10, 20, and 30 years duration of diabetes, respectively, among persons assigned to conventional treatment (mean A1c 9.6% [81 mmol/mol]), higher than among those in the intensive treatment arm (10%, 21%, 25%, respectively; mean A1c 8.9% [74 mmol/mol]). In the 325 participants with incident moderate albuminuria who were followed for up to 23 years, the 10-year cumulative incidence was 28% for severe albuminuria, 15% for impaired eGFR (eGFR <60 mL/min/1.73 m^2^ at two consecutive study visits), and 4% for ESRD (33). The 10-year cumulative incidence of regression to normoalbuminuria, however, was also common, at 40%. Lower levels of A1c, blood pressure, low-density lipoprotein (LDL) cholesterol, and triglycerides and absence of retinopathy were associated with reduced risk of kidney disease progression.

In type 2 diabetes, the incidence of elevated albuminuria in relation to diabetes duration is more difficult to characterize because of the uncertainty in dating the onset of diabetes in most studies. No relationship between duration of type 2 diabetes and the incidence of proteinuria was found in the Mayo Clinic population in Rochester, Minnesota (236), whereas in Wisconsin (237), a relationship between diabetes duration and incidence of proteinuria was stronger in persons who received insulin than in those who did not. In Pima Indians, in whom the duration of type 2 diabetes is known with greater accuracy because of systematic periodic oral glucose tolerance testing in the population, the age-sex-adjusted incidence of proteinuria, defined as urinary protein-to-creatinine ratio ≥0.5 g/g, was strongly related to duration of diabetes (238).

FIGURE 22.12 Sex- and Cohort-Specific Prevalence of Moderate and Severe Albuminuria, Pittsburgh Epidemiology of Diabetes Complications Study

Moderate albuminuria, albumin excretion rate of 30–300 mg/24 hours; severe albuminuria, albumin excretion rate >300 mg/24 hours.

Bar graph showing the prevalence of moderate and severe albuminuria was lower in 1965 to 1980 in both men and women compared to the prevalence in 1950 to 1964

SOURCE: Reference 215

FIGURE 22.13 Prevalence of Elevated Urinary Albumin Excretion, By Duration of Type 1 Diabetes

Moderate albuminuria is defined as 31–299 mg/24 hours and severe albuminuria as ≥300 mg/24 hours.

Line graph showing the prevalence of albuminuria increases with longer duration of type 1 diabetes

SOURCE: Reference 218, copyright © 1988 BMJ Publishing Group, reprinted with permission

TABLE 22.9 Prevalence of Moderate Albuminuria and Severe Albuminuria in Men and Women With Type 1 Diabetes and Without Diabetes, Wisconsin Epidemiologic Study of Diabetic Retinopathy, 1984–1986

| PERCENT
| Diabetes | | | No Diabetes
| Males (n=365) | Females (n=341) | Total (n=706) | Males (n=111) | Females (n=130) | Total (n=241)
Normal albuminuria (<0.03 g albumin/L) | 53 | 63 | 58 | 92 | 95 | 94
Moderate albuminuria (0.03–0.29 g albumin/L) | 21 | 22 | 21 | 6 | 4 | 5
Severe albuminuria (≥0.30 g protein/L) | 26 | 16 | 21 | 2 | 1 | 1

Type 1 diabetes is defined as insulin-treated diabetes in subjects diagnosed at age <30 years.

SOURCE: Reference 216, reproduced with permission, copyright © 1992 American Medical Association. All rights reserved.

A secular decline in the incidence of diabetic kidney disease has been described in type 1 diabetes (239,240,241,242,243,244). In the EDC study (241), the cumulative incidence of diabetic nephropathy, defined as persistent AER >200 µg/min in timed urine collections, was 37% lower in the 179 participants diagnosed with diabetes in 1975–1980 than in the 339 participants diagnosed in 1965–1974, after 20 years of diabetes. Among those with >25 years of diabetes duration, the declining trend was not statistically significant (Figure 22.15). The favorable trend disappeared in those with diabetes duration >35 years. Nevertheless, significant reductions in both mortality and ESRD rates in this population suggest a slower progression to kidney failure with improved management of diabetes complications. Comparable data have been reported for persons with type 1 diabetes in Sweden (242), where the cumulative incidence of persistent albuminuria (≥1 positive test by Albustix) after 20 years of diabetes decreased from 28% in persons diagnosed with type 1 diabetes in 1961–1965 to 6% in those diagnosed in 1980–1985. Furthermore, none of the 51 persons in whom type 1 diabetes was diagnosed in 1976–1980 developed persistent albuminuria during 12–16 years of follow-up. Figure 22.16 shows the cumulative incidence of persistent albuminuria in these cohorts according to the calendar year of diagnosis of diabetes. The decline in the cumulative incidence coincided with improvement in glycemic control compar-able to that in the intensively treated group in the DCCT study (245). These findings were replicated in the Steno Diabetes Center cohort from Denmark (243,244). The cumulative incidence of diabetic kidney disease, defined as persistent albuminuria, declined from 31.1% in those with onset of type 1 diabetes in 1965–1969 to 13.7% in those with onset of diabetes in 1979–1984, the most significant decline occurring in the most recent cohort (Figure 22.17) (244). This change paralleled a significant trend for earlier initiation of antihypertensive treatment following the onset of diabetes, expansion of renin-angiotensin-aldosterone system (RAAS) inhibitor usage, and sustained improvement in mean blood pressure.

FIGURE 22.14 Prevalence of Elevated Urinary Albumin Excretion in Pima Indians, By Duration of Diabetes, 1982–1988

Moderate albuminuria is defined as 31–299 mg/24 hours and severe albuminuria as ≥300 mg/24 hours.

Bar graph showing the prevalence of albuminuria increases with longer duration of type 2 diabetes

SOURCE: Reference 207

In contrast with type 1 diabetes, no secular decline in the incidence of proteinuria has been reported in type 2 diabetes. The 10-year cumulative incidence of persistent proteinuria in the predominantly Caucasian population age ≥40 years of Rochester, Minnesota, remained 12% in those diagnosed with type 2 diabetes in 1970–1979 (n=483) and those diagnosed in 1980–1989 (n=680) (246). The 20-year cumulative incidence of proteinuria reported in this study, however, was 41%, higher than the 25% cumulative incidence reported in an earlier Rochester study of individuals diagnosed with diabetes in 1945–1969 (236). These secular differences may be related in part to differences in age distributions and in diabetes diagnosis criteria between the studies. In the Pima Indian longitudinal study, in which the population was screened approximately every 2 years using 2-hour oral glucose tolerance testing, the incidence of proteinuria rose between 1967 and 2002 in response to the longer average duration of diabetes in this population in recent years (Table 22.10) (247).

The progression of kidney disease in persons with newly diagnosed type 2 diabetes in the United Kingdom Prospective Diabetes Study (UKPDS) is presented in Figure 22.18 (248,249). The rate of progression to the next level of kidney disease severity (moderate albuminuria, severe albuminuria, or elevated plasma creatinine or renal replacement therapy) was 2%–2.8% per year; the risk of death increased with increasing severity of kidney disease, with an annual rate of 1.4% for subjects with no nephropathy, 3.0% for those with moderate albuminuria, 4.6% for those with severe albuminuria, and 19.2% with elevated plasma creatinine or renal replacement therapy. Individuals with severe albuminuria were more likely to die in any year than to develop kidney failure. Progression from no nephropathy to severe albuminuria or more advanced kidney disease was low (0.1%), as was progression from moderate albumin-uria to elevated plasma creatinine or renal replacement therapy.

Although moderate albuminuria is associated historically with an inexorable progression to severe albuminuria and a decrease in the GFR of 10–15 mL/min/year, leading to ESRD (250,251), a substantial proportion of persons with type 1 or type 2 diabetes and moderate albuminuria spontaneously regress to normoalbuminuria. This observation suggests that moderate albuminuria represents reversible kidney injury rather than the onset of an inevitable progression to ESRD. In a prospective observational study of persons with type 1 diabetes and moderate albuminuria, only 19% developed severe albuminuria, whereas 59% regressed to normal albuminuria after 6 years of follow-up (36). The incidence of albuminuria reported in predominantly white populations with type 1 diabetes is lower and the rate of regression higher than those reported in African Americans with type 1 diabetes for a similar time period (252,253). The 6-year cumulative incidence of moderate albumin-uria (AER 20–200 µg/min) in 473 African Americans with type 1 diabetes was 26.0% (95% CI 20.9%–31.6%), and of severe albuminuria (AER ≥200 µg/min) 16.9% (95% CI 12.6%–21.8%), with an overall incidence of elevated albuminuria of 42.9% (95% CI 36.9%–50.0%) (Figure 22.19) (252). Among the 370 African Americans with ACR <200 µg/min at baseline, 23.5% (95% CI 19.3%–28.2%) progressed to severe albuminuria. Overall, 33.5% progressed to a worse albuminuria category, and 8.5% improved either spontaneously or due to treatment with angiotensin-converting enzyme (ACE) inhibitors or other antihypertensive medicines.

FIGURE 22.15 Incidence of Kidney Disease in Persons With Type 1 Diabetes, Pittsburgh Epidemiology of Diabetes Complications Study, 1986–2000, and Steno Clinic Population, 1933–1984

Kidney disease is defined as an albumin excretion rate >200 µg/min in at least two of three timed urine collections.

Line graph showing the incidence of kidney disease increased with longer duration of diabetes in 1 study and peaked at 17 years duration and declined afterwards in another study

SOURCE: Reference 241, copyright © 2006 American Diabetes Association, reprinted with permission from The American Diabetes Association

FIGURE 22.16 Cumulative Incidence of Persistent Albuminuria in Persons With Type 1 Diabetes Diagnosed Before Age 15 Years, by Duration of Diabetes

Persistent albuminuria is defined as ≥1 positive by Albustix. Subjects are divided into four groups based on calendar years in which diabetes was diagnosed.

* p=0.01 for difference with the group with onset of type 1 diabetes in 1961–1965

Line graph showing the cumulative incidence of persistent albuminuria by duration of diabetes decreased from the early 1960’s to the late 1970’s

SOURCE: Reference 242, copyright © 1994 Massachusetts Medical Society, reprinted with permission

FIGURE 22.17 Cumulative Incidence of Diabetic Nephropathy by Period of Onset of Type 1 Diabetes Diagnosed Before Age 15 Years, by Duration of Diabetes

Line graph showing the cumulative incidence of diabetic nephropathy by duration of diabetes decreased from the late 1960’s to the early 1980’s

SOURCE: Reference 244, copyright © 2003 American Diabetes Association, reprinted with permission from The American Diabetes Association

TABLE 22.10 Incidence of Proteinuria in Three Independent Time Periods Among Pima Indians With Type 2 Diabetes, by Diabetes Duration and Proportion of Person-Years Accumulating in Short and Long Duration Categories, 1967–2002

| TIME PERIOD
| 1967–1978 | | | 1979–1990 | | | 1991–2002
| Cases | Person-Years | Rate^*^ | Cases | Person-Years | Rate^*^ | Cases | Person-Years | Rate^*^
Diabetes duration (years)
<10 | 31 | 2,383.8 | 13.0 | 22 | 1,846.2 | 11.9 | 32 | 2,055.9 | 15.6
10–15 | 32 | 598.6 | 53.5 | 36 | 712.3 | 50.5 | 31 | 620.2 | 50.0
15–20 | 17 | 176.9 | 96.1 | 47 | 493.0 | 95.3 | 48 | 439.6 | 109.2
≥20 | 8 | 78.7 | 101.6 | 32 | 231.5 | 138.2 | 30 | 295.4 | 101.6
Unadjusted rate | 88 | 3,238.0 | 27.2 | 137 | 3,283.0 | 41.7 | 141 | 3,411.1 | 41.3
Age-sex-adjusted rate (95% confidence interval) | | | 24.3 (18.7–30.0) | | | 35.4 (28.1–42.8) | | | 38.9 (31.2–46.5)
Proportion of person-years of follow-up in persons with ≥10 years duration of diabetes (%) | | 26 | | | 44 | | | 40

Proteinuria is defined as urinary protein-to-creatinine ratio ≥0.5 g/g.

* Rate is reported as cases per 1,000 person-years at risk.

SOURCE: Reference 247, copyright © 2006 Elsevier, reprinted with permission

In general, the proportion of persons with type 2 diabetes who regress from moderate albuminuria to normoalbuminuria is 30%–54%, while the frequency of progression to overt proteinuria is 12%–36% (254,255,256). Moderate albuminuria of short duration, use of RAAS inhibitors, lower A1c (<6.9% [<52 mmol/mol]), and systolic blood pressure <129 mmHg are independently associated with regression. A higher likelihood of progression than regression of diabetic kidney disease was found in a large population-based study of persons with type 2 diabetes and hypertension, all members of a managed care organization (257), who had at least two ACR measurements during a mean follow-up of 5 years. At baseline, 57% had normal ACR (<3.4 mg/mmol), 31% had moderate albuminuria (3.4–33.8 mg/mmol), and 12% had severe albuminuria (≥33.9 mg/mmol). Among those with normal ACR at baseline, 46% developed elevated ACR by the end of follow-up; of those with moderate albumin-uria, 20% developed severe albuminuria, whereas 21% regressed to normal ACR; and among those with severe albuminuria, 4% developed ESRD and 31% regressed to moderate albuminuria. When included in a multivariable adjusted model, duration of diabetes, antihypertensive treatment, body mass index (BMI), A1c, and being African American were positively associated with progression to elevated ACR, whereas age, GFR, systolic blood pressure, and treatment with RAAS inhibitors were positively associated with progression to ESRD in persons with severe albuminuria. Among 750 American Indians from Arizona, Oklahoma, and North and South Dakota age 45–74 years in the Strong Heart Study, albuminuria was measured in 1989–1991 (baseline), 1993–1995 (second examination), and 1997–1999 (third examination) (258). Among those with normal ACR at baseline, 67% remained so and 33% developed elevated albuminuria (29% moderate albuminuria and 4% severe albuminuria) by the second examination. More participants with normal albuminuria at the second examination remained normoalbuminuric (77%), and 23% developed elevated albuminuria (19% moderate albuminuria and 4% severe albuminuria) by the third examination, suggesting a decline in onset of kidney disease in the later years. Risk factors for onset of elevated albuminuria were higher A1c, systolic blood pressure, higher baseline ACR, smoking, hypoglycemic treatment, and longer diabetes duration. Participants with a baseline ACR between 10 and 30 mg/g had nearly threefold higher risk of elevated ACR over a 4-year period (OR 2.7, 95% CI 1.9–3.9) than those with baseline ACR <5 mg/g (258). The cumulative incidence of elevated ACR increased with duration of diabetes (p<0.01) and was similar in men and women in the three study centers (Figure 22.20).

FIGURE 22.18 Chronic Kidney Disease Progression in Persons With New-Onset Type 2 Diabetes, United Kingdom Prospective Diabetes Study, 1977–1997

Percentages represent annual rates with 95% confidence intervals.

Flow chart showing annual progression to the next stage of C K D was 2% to 2.8% and death occurred in 1.4% with no nephropathy increasing to 19.2% in those with elevated plasma creatinine or E S R D

SOURCE: Reference 248, copyright © 2003 Elsevier, reprinted with permission

### Diabetic Kidney Disease as a Risk Factor for ESRD, Cardiovascular Disease, and Death

A new analysis of the NHANES 1999–2004 conducted for Diabetes in America showed that elevated albuminuria and low GFR are associated with ESRD, fatal and nonfatal CVD, and all-cause mortality (Table 22.11). For albuminuria, these associations are a continuum, starting at levels well below the 30 mg/g threshold that defines moderate albuminuria (259,260,261,262). Among American Indians age 45–74 years in the Strong Heart Study (259) who were free of CVD at baseline, ACR <30 mg/g was a strong and independent predictor of all cardiovascular events, including nonfatal and fatal CVD, and these associations were similar in individuals with or without diabetes. In those with diabetes, the adjusted risks for all, nonfatal, and fatal CVD events increased by 20% (hazard ratio [HR] 1.20, 95% CI 1.07–1.34), 13% (HR 1.13, 95% CI 0.99–1.28), and 48% (HR 1.48, 95% CI 1.17–1.87), respectively, for each doubling of ACR within the normal range.

Among persons with diabetes participating in the NHANES III, those with the highest ACR levels (ACR ≥300 mg/g) and lowest eGFR (eGFR 15–59 mL/min/1.73 m^2^) had a 2.7-fold higher risk for cardiovascular mortality and a 2.5-fold higher risk for all-cause mortality, relative to those with normal ACR and eGFR ≥90 mL/min/1.73 m^2^ (263). Similar associations were found in participants without diabetes; however, those with diabetes had greater absolute risks for these outcomes. Adjustments for diabetes duration and cardiovascular risk factors did not change the significance of these associations, suggesting that CKD is a risk amplifier, with much of the excess CVD in diabetes occurring in persons with diabetic kidney disease.

FIGURE 22.19 Six-Year Incidence of Any Proteinuria in African American Men and Women With Type 1 Diabetes, by Duration of Diabetes at the Baseline Examination, New Jersey 725 Study, 1993–1998

Line graph showing the 6-year incidence of proteinuria was 42.9% overall and highest among those with 5 to 9 years duration at baseline

SOURCE: Reference 252, copyright © 2007 American Diabetes Association, reprinted with permission from The American Diabetes Association

FIGURE 22.20 Four-Year Cumulative Incidence of Elevated Albuminuria in American Indians, by Duration of Diabetes, Sex, and Study Site, Strong Heart Study

ACR, albumin-to-creatinine ratio.

Bar graph showing the 4-year cumulative incidence of albuminuria was similar in men and women and higher among people with a longer duration of diabetes

SOURCE: Reference 258

Nearly all of the excess mortality associated with either type of diabetes is found in persons with severe albuminuria (35,264,265), primarily from kidney disease or CVD in type 1 diabetes (264,266), from CVD in whites with type 2 diabetes (267), and from CVD or kidney disease in Pima Indians with type 2 diabetes (265,268). The 20-year mortality in 658 persons with type 1 diabetes in the EDC study is shown in Tables 22.12 and 22.13 (269). Individuals who maintained normal levels of albumin excretion had near-normal survival (standardized mortality ratio [SMR] 1.2, 95% CI 0.5–1.9), and they were more likely to die from non-diabetes-related causes than individuals who had elevated albuminuria (AER ≥20 µg/min) (269). Other studies in persons with more than 30 years duration of type 1 diabetes show similar associations (270,271).

An analysis of secular trends in the incidence of ESRD and mortality in patients with type 1 diabetes and severe albumin-uria from the Joslin Clinic, however, found no significant decline in pre-ESRD death rate, progression to ESRD, or post-ESRD death rate from 1991 to 2004, despite both widespread adoption of kidney protective treatments during the same period and significant improvements in blood pressure and total serum cholesterol concentration (272,273). Sixty-nine percent of either pre- or post-ESRD excess mortality was attributable to CVD. Moderate and severe albuminuria independently predicted all-cause mortality in a monotonic fashion in the FinnDiane cohort, a cohort representing 16% of the population with type 1 diabetes in Finland (217). During 7 years of follow-up, the overall death rate in persons with moderate albuminuria was nearly three times that observed in the general Finnish population (adjusted SMR 2.8, 95% CI 2.0–4.2), with CVD representing 56% of these deaths. Severe albuminuria was associated with nine times the death rate observed in the age- and sex-matched general population (adjusted SMR 9.2, 95% CI 8.1–10.5), 45% of these being caused by CVD. Indeed, the impact of albuminuria level on mortality risk was equivalent to that of preexisting macrovascular disease, as defined by a history of myocardial infarction, unstable angina requiring hospitalization, coronary revascularization, stroke, carotid surgery, peripheral revascularization, or amputation for critical limb ischemia. Other major causes of death included infections and cancer. By contrast, overall death rates in persons with normal ACR were equivalent to those in the general population (adjusted SMR 0.8, 95% CI 0.5–1.1), regardless of diabetes duration, indicating that diabetic kidney disease is a major driver of excess mortality in type 1 diabetes. Irrespective of albuminuria level, the eGFR was independently associated with mortality, but in a U-shaped fashion, as shown in Figure 22.21 (217), possibly reflecting confounding from other morbid conditions unrelated to kidney disease at high eGFR levels. The non-linear association reflects serum creatinine confounding due to such factors as low or reduced muscle mass, increased tubular secretion, and extrarenal elimination of creatinine. Moreover, measurement imprecision is greater at lower concentrations of serum creatinine, compounding the difficulty of interpreting serum creatinine levels in those with normal or high-normal GFR (274).

TABLE 22.11 Crude All-Cause and Cause-Specific Death Rates in Adults With Diabetes and Chronic Kidney Disease, U.S., 1999–2004

CHARACTERISTICS | SAMPLE SIZE | DEATH RATE (STANDARD ERROR)^*^
CHARACTERISTICS | SAMPLE SIZE | All Causes | Cardiovascular Disease | Cancer
All | 771 | 45.1 (4.10) | 20.7 (2.95) | 6.4 (2.28)^1^
Age (years)
20–44 | 62 | ^3^ | ^3^ | ^3^
45–64 | 228 | 23.1 (5.88) | 8.1 (3.92)^2^ | ^3^
≥65 | 481 | 70.8 (6.29) | 34.2 (4.57) | 10.4 (3.98)^1^
Sex
Men | 410 | 50.8 (6.29) | 25.9 (4.44) | 7.0 (2.75)^1^
Women | 361 | 38.8 (5.27) | 14.7 (3.31) | ^3^
Race/ethnicity
Non-Hispanic white | 313 | 55.4 (6.53) | 26.0 (4.90) | 9.2 (3.53)^1^
Non-Hispanic black | 179 | 45.2 (7.17) | 19.1 (3.83) | ^3^
Mexican American | 213 | 26.0 (5.30) | 12.4 (3.57) | ^3^
CKD stages 1–2 | 403 | 24.6 (4.21) | 9.0 (2.69) | 5.9 (2.47)^2^
CKD stages 3–5 | 368 | 74.7 (8.20) | 37.4 (6.09) | 7.1 (3.38)^2^

Deaths are ascertained through 2006. Diabetes is defined as self-reported diabetes or undiagnosed diabetes based on A1c ≥6.5% or fasting plasma glucose ≥126 mg/dL. Conversions for A1c and glucose values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; CKD, chronic kidney disease.

* Death rate per 1,000 person-years

1 Relative standard error >30%–40%

2 Relative standard error >40%–50%

3 Estimate is too unreliable to present; ≤1 case or relative standard error >50%.

SOURCE: National Health and Nutrition Examination Surveys 1999–2004 and the Linked Mortality File through 2006

TABLE 22.12 Death Rates in Persons With Type 1 Diabetes by Sex, Age, Race, and Baseline Kidney Damage Categories, Pittsburgh Epidemiology of Diabetes Complications Study, 1986–2008

CHARACTERISTICS | N (%) | FOLLOW-UP TIME (YEARS) | | DEATHS N (%) | DEATH RATE/100 P-YRS (95% CI)
CHARACTERISTICS | N (%) | Median | Total | DEATHS N (%) | DEATH RATE/100 P-YRS (95% CI)
All | 658 | 20.1 | 11,870 | 152 (23.1) | 1.3 (1.1–1.5)
Sex
Men | 333 (50.6) | 20.0 | 5,922 | 85 (26.2) | 1.4 (1.1–1.7)
Women | 325 (49.4) | 20.2 | 5,948 | 67 (21.1) | 1.1 (0.9–1.4)
Race
White | 643 (97.7) | 20.1 | 11,610 | 147 (22.9) | 1.3 (1.1–1.5)
Black | 15 (2.3) | 20.2 | 260 | 5 (33.3) | 1.9 (0.2–3.6)
AER
Normal | 347 (52.7) | 20.4 | 6,851 | 24 (7.1) | 0.3 (0.2–0.5)
Moderate | 140 (21.3) | 20.1 | 2,510 | 39 (28.1) | 1.6 (1.1–2.0)^*^
Severe | 146 (22.2) | 19.0 | 2,275 | 69 (47.3) | 3.0 (2.3–3.8)^*^,^†^
ESRD | 25 (3.8) | 8.6 | 234 | 20 (80.0) | 8.6 (4.8–12.3)^*^,^†^,^‡^

Albumin excretion rate (AER): <20 μg/min, normal; 20–200 μg/min, moderate; >200 μg/min, severe, in at least two of three timed urine collections. CI, confidence interval; ESRD, end-stage renal disease; p-yrs, person-years.

* p<0.001 for rate ratio compared with normal AER

† p<0.001 for rate ratio compared with moderate AER

‡ p<0.001 for rate ratio compared with severe AER

SOURCE: Reference 269, copyright © 2010 Springer, reprinted with permission

Likewise, in type 2 diabetes, death rates due to both overall and cardiovascular causes are greatly increased with elevated albuminuria (275,276,277,278). Among 1,993 Pima Indians (55.9% with type 2 diabetes, the only type of diabetes occurring in this population, even at young ages) followed for a median of 11 years, death rates from natural causes increased with worsening kidney function in both nondiabetic and diabetic subjects (268). Figure 22.22 shows that death rates in nondiabetic and diabetic subjects without kidney disease were virtually identical and increased similarly with worsening kidney disease in both groups, suggesting that kidney disease rather than diabetes per se is the major determinant of increased mortality among the diabetic population. The higher overall mortality in those with longer duration of diabetes is due primarily to the greater proportion of person-years of follow-up falling in the categories of worse kidney function (Figure 22.22C). The presence of kidney disease was associated with excess mortality from diabetic kidney disease, CVD, infections, and malignancy in the Pima Indians with diabetes and from infections in those without diabetes. In a cross-sectional analysis including American Indians with type 2 diabetes in the Strong Heart Study (685 with normal albuminuria, 519 with moderate albumin-uria, and 372 with severe albuminuria), participants with severe albuminuria were more likely to experience left ventricular systolic and diastolic dysfunction than those with normal ACR (Figure 22.23) (279). Further, among 4,081 American Indians, 45% with diabetes, reduced eGFR (<90 mL/min/1.73 m^2^) was associated with increased risk of CVD events, including coronary heart disease, stroke, and heart failure during a median follow-up of 15 years (280). The associations between eGFR measure and CVD events were attenuated after adjusting for albuminuria.

TABLE 22.13 Mortality Risk and Standardized Mortality Ratios in Participants With Type 1 Diabetes, Pittsburgh Epidemiology of Diabetes Complications Study, 1986–2008

VARIABLE | HAZARD RATIO (95% CI) | | ADJUSTED SMR^†^ (95% CI)
VARIABLE | Unadjusted | Adjusted^*^ | ADJUSTED SMR^†^ (95% CI)
10-year follow-up
AER
Normal (ref) | 1.0 | 1.0 | 1.3 (0.2–2.5)
Moderate | 6.8 (2.4–19.1) | 3.5 (1.1–11.4) | 6.6 (3.0–10.1)
Severe | 16.3 (6.4–42.0) | 5.2 (1.6–16.1) | 14.2 (9.2–19.2)
ESRD | 68.6 (25.1–187.6) | 28.8 (8.7–95.9) | 38.9 (19.8–57.9)
20-year follow-up
AER
Normal (ref) | 1.0 | 1.0 | 2.0 (1.2–2.8)
Moderate | 4.5 (2.7–7.5) | 2.4 (1.4–4.3) | 6.4 (4.4–8.4)
Severe | 9.3 (5.8–14.6) | 4.0 (2.3–7.0) | 12.5 (9.5–15.4)
ESRD | 28.9 (15.9–52.6) | 9.0 (4.3–18.7) | 29.8 (16.8–42.9)

Albumin excretion rate (AER): <20 μg/min, normal; 20–200 μg/min, moderate; >200 μg/min, severe, in at least two of three timed urine collections. AER, albumin excretion rate; BP, blood pressure; CI, confidence interval; ESRD, end-stage renal disease; ref, reference; SMR, standardized mortality ratio.

* Variables in the model: duration of diabetes, sex, race, waist-to-hip ratio, glycosylated hemoglobin (A1c), systolic BP, diastolic BP, BP medication use, high-density lipoprotein cholesterol, non-high-density lipoprotein cholesterol, white blood cells, estimated glomerular filtration rate, presence of macrovascular disease, presence of proliferative retinopathy, and ever smoker

† Adjusted for age, race, and sex

SOURCE: Reference 269, copyright © 2010 Springer, reprinted with permission

FIGURE 22.21 Risk of Death Associated With Estimated Glomerular Filtration Rate in Type 1 Diabetes

Relative hazard computed in persons with type 1 diabetes: (A) without end-stage renal disease, (B) with normal albuminuria, (C) with moderate albuminuria, and (D) with severe albuminuria. Albuminuria is defined by a urinary albumin excretion rate <20 µg/min (normal albuminuria), 20–200 µg/min (moderate albuminuria), and >200 µg/min (severe albuminuria), in two of three consecutive urine collections. Line indicates adjusted point estimates for cubic regression spline, and shaded areas show 95% confidence intervals. GFR, glomerular filtration rate.

Line graphs showing the relative hazard of death associated with G F R was generally u-shaped regardless of albuminuria status, with the lowest risk between a G F R of 60 and 90

SOURCE: Reference 217, copyright © 2009 American Diabetes Association, reprinted with permission from The American Diabetes Association

Fewer studies have focused on the noncardiovascular causes of mortality associated with diabetic kidney disease. Persons with CKD are three to four times more likely to have a poor prognosis after acquiring infections than the non-CKD population (281,282,283). Persons with diabetes have a higher risk of community-acquired lower respiratory tract infection, pneumonia, and sepsis with declining eGFR and increasing ACR, independent of age, sex, smoking status, and comorbid conditions of diabetes (282). Among hemodialysis patients with diabetes, adjusted hospitalization rates for infections are 0.5 per patient-year (1), similar to the rate of hospitalizations for CVD and higher than among patients with ESRD due to other causes than diabetes. Infections represented the second leading cause of death (15.9%) after CVD (55.8%) among those who initiated hemodialysis between 1995 and 2009 due to diabetes; the leading fatal infections on dialysis were septicemia and pneumonia (284). Other causes of death in this cohort were malignancy (2.8%), withdrawal from dialysis (5.2%), and unknown or unidentified causes (9.6%). The leading causes of death were the same for each racial/ethnic group (284). Although some reports suggest that both kidney disease, particularly ESRD, and diabetes increase the risk of death from several types of cancer (285,286,287), this is not a uniform finding (288,289,290,291).

Quantitative information about ACR adds significant predictive value to eGFR about the risk of death or ESRD, and therefore, using both ACR and eGFR is significantly better for predicting these outcomes than using either measure alone (292,293,294). An analysis conducted in 10,640 persons with type 2 diabetes enrolled in the Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation (ADVANCE) trial (293) showed similar contributions of high ACR and low eGFR to cardiovascular and kidney events (Figure 22.24). These findings concur with those from a systematic review of the association between microvascular and macrovascular disease in type 2 diabetes (295), which showed an approximately twofold increased risk for cardiovascular events associated with albuminuria or reduced eGFR (Table 22.14) (260,295,296,297,298,299,300,301,302,303,304,305,306,307,308). The strength of these associations remained after adjustments for multiple confounders, suggesting that microvascular and macro-vascular disease in type 2 diabetes may share similar pathophysiologic mechanisms. A meta-analysis of 1,024,977 participants (nearly 13% with diabetes) from 30 general population and high-risk cardiovascular cohorts and 13 CKD cohorts indicated that while the absolute risks for all-cause and cardiovascular mortality are higher in the presence of diabetes, the relative risks of ESRD or death by eGFR and ACR are similar with or without diabetes (309). These findings underscore the importance of kidney disease per se as a predictor of important clinical outcomes, regardless of the underlying cause of kidney disease. Additional information about mortality and causes of death in persons with diabetes can be found in Chapter 35 Mortality in Type 1 Diabetes and Chapter 36 Mortality Trends in Type 2 Diabetes.

FIGURE 22.22 Trends in Age-Sex-Adjusted Death Rates From Natural Causes and Cardiovascular Disease in American Indians With and Without Diabetes, by Severity of Kidney Disease

Trends in age- and sex-adjusted death rates from (A) natural causes and (B) cardiovascular disease (CVD). The bars represent mortality rates stratified by diabetes and its duration in the four kidney disease categories. The line shows overall death rates by diabetes and its duration, indicating a lesser effect of duration than of kidney function on mortality. Panel (C) shows the frequency distribution of person-years stratified by diabetes and its duration in the four kidney disease categories. The fraction of person-years of follow-up among persons with normal kidney function ranged from 96% in subjects without diabetes to 53% in those with 20–30 years of diabetes. Conversely, the fraction of person-years among persons on RRT ranged from 0.4% in subjects without diabetes to 12% in those with 20–30 years of diabetes. Proteinuria was defined by a protein-to-creatinine ratio ≥0.5 g protein/g creatinine, reflecting an approximate protein excretion rate of at least 0.5 g/day. High SCr is defined as SCr ≥133 µmol/L (1.5 mg/dL) in men and ≥124 µmol/L (1.4 mg/dL) in women. RRT, renal replacement therapy; SCr, serum creatinine.

* Insufficient data

† Rate is null.

Bar graph showing death rate is higher among people with a longer duration of diabetes and those with worse kidney disease

SOURCE: Reference 268

FIGURE 22.23 Prevalence of Subnormal Left Ventricular Midwall Shortening and Diastolic Dysfunction in American Indians With Type 2 Diabetes, by Albuminuria, Strong Heart Study, 1993–1995

Comparison between each group was made using chi-squared statistics with Bonferroni correction. Subnormal stress-corrected MWS is defined as stress-corrected MWS <88.7%. Abnormal diastolic function is defined as transmitral early diastolic Doppler flow/atrial phase LV filling ratios of <0.6 (compatible with impaired early diastolic relaxation) and >1.5 (compatible with restrictive LV filling). ACR, albumin-to-creatinine ratio; LV, left ventricle; MWS, midwall shortening.

* p=0.02 relative to ACR <30 mg/g

† p<0.001 relative to ACR <30 mg/g

Bar graph showing the people with macroalbuminuria were more likely to have subnormal left ventricular mid-wall shortening and diastolic dysfunction than those without albuminuria

SOURCE: Reference 279

FIGURE 22.24 Association of (A) Urinary Albumin-to-Creatinine Ratio and (B) Estimated Glomerular Filtration Rate Levels During Follow-Up With the Risk for Cardiovascular Events

Closed and open squares represent hazard ratios (HRs) in subgroups for eGFR <60 and ≥60 mL/min/1.73 m^2^, UACR <30 and ≥30 mg/g, or SBP <140 and ≥140 mmHg. Hazard ratios are adjusted for age; sex; follow-up variables, including eGFR (or UACR); SBP; glycosylated hemoglobin (A1c); low-density lipoprotein (LDL) cholesterol; high-density lipoprotein (HDL) cholesterol; triglycerides; body mass index; randomized study treatment; and baseline covariates, including duration of diabetes, history of hypertension, history of macrovascular disease, electrocardiogram abnormalities, current smoking, and current drinking. The hazard ratios and 95% confidence intervals for the regression lines were corrected with the regression dilution attenuation coefficient of log-transformed UACR (1.98) and log-transformed eGFR (1.96). CI, confidence interval; eGFR, estimated glomerular filtration rate; SBP, systolic blood pressure; UACR, urinary albumin-to-creatinine ratio.

Line graphs showing that among those with diabetes, adjusted hazard ratios for cardiovascular events was higher at higher levels of U A C R and at lower levels of G F R

SOURCE: Reference 293, copyright © 2009 American Society of Nephrology, reprinted with permission

TABLE 22.14 Prospective Studies With at Least 200 Type 2 Diabetes Subjects That Evaluated Hard Cardiovascular Endpoints

STUDY/LOCATION, YEARS OF DATA COLLECTION (REF.) | N | NEPHROPATHY MARKER | CARDIOVASCULAR ENDPOINT | HAZARD RATIO OR RELATIVE RISK (95% CI)
Japan (Japan Diabetes Clinical Data Management [JDDM] Study Group), 2004–2005 (296) | 3,002 | Microalbuminuria - ACR | Composite, CVD | 1.7 (1.22–2.38)
Hong Kong, NR (297) | 4,416 | Albuminuria - ACR | Composite, CVD events
Hong Kong, NR (297) | 4,416 | Microalbuminuria | Composite, CVD events | 1.68 (1.11–2.55)
Hong Kong, NR (297) | 4,416 | Macroalbuminuria | Composite, CVD events | 2.45 (1.51–3.99)
Hong Kong, 1995–2000 (298) | 4,421 | Albuminuria - ACR | Composite, CVD events | 1.85 (1.07–3.18)
Spain, 1994–1998 (299) | 423 | Microalbuminuria - UAE | Composite, CVD events | 2.30 (1.30–3.80)
Spain, 1994–1998 (299) | 423 | Microalbuminuria - UAE | CVD death | 2.30 (1.30–3.80)
HOPE study and MICRO HOPE substudy; North and South America and Europe, 1994–1999 (260) | 3,498 | Microalbuminuria - ACR | Composite, CVD events | 1.84 (1.46–2.31)
Hong Kong, 1995–2005 (300) | 7,067 | Albuminuria | Composite, CHD events
Hong Kong, 1995–2005 (300) | 7,067 | Microalbuminuria | Composite, CHD events | 1.34 (0.97–1.85)
Hong Kong, 1995–2005 (300) | 7,067 | Macroalbuminuria | Composite, CHD events | 1.76 (1.19–2.58)
Thailand, 1997–2001 (301) | 229 | Proteinuria | Composite, CHD events | 4.41 (1.18–16.45)
Finland, 1982–2001 (302) | 720 | Proteinuria | CVD death | 1.60 (1.00–2.60)
Casale Monferrato Study, Italy, 1991–2001 (303) | 1,538 | Albuminuria - AER | CVD death
Casale Monferrato Study, Italy, 1991–2001 (303) | 1,538 | Microalbuminuria | CVD death | 1.20 (0.93–1.57)
Casale Monferrato Study, Italy, 1991–2001 (303) | 1,538 | Macroalbuminuria | CVD death | 1.45 (1.16–1.82)
Italy, NR (304) | 683 | Microalbuminuria - UAE | CVD death | 2.01 (1.15–3.68)
Wisconsin Epidemiologic Study of Diabetic Retinopathy (WESDR), 1980–1996 (305) | 840 | Microalbuminuria - UAE | CVD death | 1.84 (1.42–2.40)
Hong Kong, 1995–2005 (306) | 7,209 | Albuminuria - ACR | Stroke | 1.70 (1.45–2.00)
United Kingdom Prospective Diabetes Study (UKPDS), 1977–1991 (307) | 3,776 | Albuminuria - ACR | Stroke | 2.30 (1.40–4.00)
Israel, 1999–2003 (308) | 269 | Reduced eGFR | Cardiac events | 2.20 (1.10–4.46)

Definitions of composite endpoints: Cardiovascular events were defined as MI, angina, revascularization, heart failure, stroke, lower limb amputation (297); CVD death, hospitalization for angina, MI, stroke, heart failure or revascularization (298); unstable angina requiring revascularization, fatal or nonfatal MI, fatal or nonfatal stroke, lower leg amputation (299); MI, stroke or CVD death (260). CHD events were defined as MI, nonfatal ischemic heart disease, CHD death (306); or MI, angina, sudden death, fatal or nonfatal CHF (301). Cardiac events were defined as confirmed MI (on the basis of cardiac enzymes and electrocardiogram evidence), unstable angina and coronary revascularization (308).

Criteria for albuminuria: ACR: ≥30 and <300 mg/g in at least two of three consecutive random samples (296); 3.5–25 mg/mmol (moderate) and ≥25–150 mg/mmol (severe) on spot urine (297,298); ≥2 mg/mmol (260); ≥2.5 mg/mmol and <25 mg/mmol in men or ≥3.5 mg/mmol and <25 mg/mmol in women (moderate) and ≥25–150 mg/mmol (severe) (300,306); ≥50 mg/L and <300 mg/L relative to mean urine creatinine concentration (11 mmol/L in men and 8 mmol/L in women) (306); UAE: 30–300 mg/24 hours (299,304) and ≥0.03 g/L in spot urine (305); AER 2–200 μg/min (moderate) and ≥200 μg/min (severe) in a timed overnight sample (303). Criteria for proteinuria: ≥1+ at least twice without pyuria (301); total urinary protein measured in morning spot urine, ≥0.1 g/L and ≥0.2 g/L (302). Criteria for reduced eGFR: creatinine clearance <60 mL/min/1.73 m^2^ (298). ACR, urinary albumin-to-creatinine ratio; CHD, coronary heart disease; CVD, cardiovascular disease; eGFR, estimated glomerular filtration rate; MI, myocardial infarction; NR, not reported; UAE, urinary albumin excretion.

SOURCE: Reference 295, copyright © 2011, reprinted with permission from Elsevier; and references listed within the table

## End-Stage Renal Disease

### Prevalence of Diabetic ESRD

Kidney failure or ESRD is the most advanced stage of CKD, requiring renal replacement therapy, such as dialysis or kidney transplant, for survival. Since 1988, all persons receiving treatment for ESRD, regardless of age and insurance coverage, are included in the United States Renal Data System (USRDS) registry (1). Consequently, the annual data report published by the USRDS contains the most complete and reliable information on treated ESRD in the United States. Table 22.15 summarizes the incidence and prevalence of treated ESRD according to demographic characteristics, primary diagnosis, and treatment modality in the United States in 2012 (1). In that year, 114,813 new cases of dialysis and transplant were added to the national registry, of which 50,534 (44%) had kidney disease attributed to diabetes. Diabetes is the single largest cause of ESRD in the United States (Figure 22.25) (1). In 1985, the adjusted prevalence of treated ESRD attributed to diabetes was 103 cases per million population, these patients accounting for 19% of prevalent treated ESRD in the United States; by 2012, the prevalence had risen to 731 cases per million population, representing 35% of prevalent treated ESRD in the United States (44% of dialysis patients and 23% of kidney transplant patients) (Table 22.15) (1). An increasing prevalence of diabetes and improved CVD survival are responsible, in part, for this growth (Figure 22.26) (310). About 30% of persons with type 1 diabetes and 10%–40% of those with type 2 diabetes eventually develop kidney failure. Because type 2 is the predominant type of diabetes, it also far exceeds type 1 diabetes as the cause of diabetes-related ESRD. Of the 239,837 prevalent cases of ESRD with diabetes at the end of 2012, type 2 diabetes was responsible for 207,145 (86%) (Table 22.16) (1).

TABLE 22.15 Summary Statistics on Reported End-Stage Renal Disease Treatment, by Age, Sex, Race/Ethnicity, and Primary Diagnosis, U.S., 2012

CHARACTERISTICS | INCIDENCE^*^ | | | DECEMBER 31 POINT PREVALENCE | | | | | | | KIDNEY TRANSPLANTS
CHARACTERISTICS | Count | Percent | Adj. Rate^†^ | Count | Percent | Adj. Rate^†^ | Dialysis^‡^ | Percent | Tx^‡^ | Percent | Deceased Tx^‡^ | Living Donor | ESRD Deaths^§^
All - unadjusted rate^‖^ | | | 358.6 | | | 1,968.20 | | | | | Total 17,330^#^
All - adjusted | 114,813 | 100 | 353.2 | 636,905 | 100 | 1,942.90 | 450,602^**^ | 100 | 186,303 | 100 | 11,535 | 5,617 | 88,638
Age (years)^††^
0–19 | 1,163 | 1 | 13.1 | 7,545 | 1.2 | 83.1 | 2,060 | 0.5 | 5,485 | 2.9 | 549 | 350 | 84
20–44 | 13,162 | 11.5 | 122.2 | 101,994 | 16 | 938 | 59,045 | 13.1 | 42,949 | 23.1 | 2,918 | 1,925 | 3,929
45–64 | 45,069 | 39.3 | 570.2 | 283,021 | 44.4 | 3,550.10 | 188,571 | 41.8 | 94,450 | 50.7 | 5,851 | 2,549 | 26,555
65–74 | 27,933 | 24.3 | 1,270.10 | 140,238 | 22 | 6,301.80 | 106,101 | 23.5 | 34,137 | 18.3 | 1,928 | 696 | 24,563
≥75 | 27,486 | 23.9 | 1,618.40 | 104,107 | 16.3 | 6,261.10 | 94,825 | 21 | 9,282 | 5 | 247 | 76 | 33,507
Sex
Men | 65,842 | 57.3 | 446 | 363,497 | 57.1 | 2,396.70 | 252,526 | 56 | 110,971 | 59.6 | 6,973 | 3,483 | 49,939
Women | 48,971 | 42.7 | 278 | 273,312 | 42.9 | 1,558.40 | 198,006 | 43.9 | 75,306 | 40.4 | 4,520 | 2,113 | 38,696
Race/ethnicity
White | 76,089 | 66.3 | 279.2 | 383,534 | 60.2 | 1,431.80 | 252,053 | 55.9 | 131,481 | 70.6 | 6,892 | 4,450 | 59,868
Black/African American | 31,398 | 27.3 | 908 | 200,797 | 31.5 | 5,670.50 | 164,211 | 36.4 | 36,586 | 19.6 | 3,547 | 718 | 23,868
American Indian | 1,273 | 1.1 | 411.5 | 8,154 | 1.3 | 2,599.50 | 6,310 | 1.4 | 1,844 | 1 | 135 | 41 | 1,012
Asian | 5,840 | 5.1 | 378.9 | 35,878 | 5.6 | 2,271.80 | 25,230 | 5.6 | 10,648 | 5.7 | 809 | 352 | 3,400
Other | 50 | 0 | | 5,860 | 0.9 | | 2,515 | 0.6 | 3,345 | 1.8 | 75 | ^‡‡^ | 490
Hispanic | 17,024 | 14.8 | 501.3 | 106,308 | 16.7 | 2,931.90 | 79,352 | 17.6 | 26,956 | 14.5 | 1,956 | 804 | 11,433
Non-Hispanic | 97,789 | 85.2 | 340.5 | 530,597 | 83.3 | 1,857.80 | 371,250 | 82.4 | 159,347 | 85.5 | 9,579 | 4,813 | 77,205
Primary diagnosis
Diabetes | 50,534 | 44 | 154.3 | 239,837 | 37.7 | 731 | 197,079 | 43.7 | 42,758 | 23 | 3,355 | 1,081 | 40,795
Hypertension | 32,610 | 28.4 | 101.1 | 159,049 | 25 | 489.4 | 129,092 | 28.6 | 29,957 | 16.1 | 2,505 | 833 | 24,975
Glomerulonephritis | 9,115 | 7.9 | 28.3 | 106,012 | 16.6 | 325.8 | 52,841 | 11.7 | 53,171 | 28.5 | 2,549 | 1,679 | 6,828
Cystic kidney disease | 2,530 | 2.2 | 7.9 | 29,881 | 4.7 | 92.4 | 11,526 | 2.6 | 18,355 | 9.9 | 832 | 620 | 1,548
Urologic disease | 538 | 0.5 | 1.6 | 7,447 | 1.2 | 22.9 | 3,576 | 0.8 | 3,871 | 2.1 | 133 | 91 | 589

Adj, adjusted; ESRD, end-stage renal disease; Tx, transplant; USRDS, United States Renal Data System.

* Incident counts include all known ESRD persons, regardless of any incomplete data on patient characteristics and of U.S. residency status.

† Includes only residents of the 50 states and Washington, D.C. Rates in the first row are unadjusted. All other rates are adjusted for age, race, and/or sex using the estimated 2011 U.S. resident population as the standard population. All rates are per million population. Rates by age are adjusted for race and sex. Rates by sex are adjusted for race and age. Rates by race are adjusted for age and sex. Rates by disease group and total adjusted rates are adjusted for age, sex, and race. Adjusted rates do not include persons with other or unknown race.

‡ Persons are classified as receiving dialysis or having a functioning transplant. Those whose treatment modality on December 31 is unknown are assumed to be receiving dialysis. Includes all Medicare and non-Medicare ESRD persons, as well as persons in the U.S. territories and foreign countries.

§ Deaths are not counted for persons whose age is unknown.

‖ Unadjusted total rates include all ESRD persons in the 50 states and Washington, D.C.

# Total transplants known to the USRDS

** Includes persons whose modality is unknown.

†† Age is computed at the start of therapy for incidence, on December 31 for point prevalence, at the time of transplant for transplants, and on the date of death for death.

‡‡ Values for cells with 10 or fewer persons are suppressed.

SOURCE: Reference 1

FIGURE 22.25 Trends in Incident ESRD Cases and ESRD Incidence Rate, by Primary Diagnosis of ESRD, 1980–2012

ESRD, end-stage renal disease.

* Adjusted for age, sex, and race. Standardized to the 2011 U.S. population.

Line graphs showing diabetes is a bigger contributor to E S R D than hypertension, glomerulonephritis, and cystic kidney

SOURCE: Reference 1

FIGURE 22.26 Incident ESRD Cases (Line), and Increase in ESRD Attributable to Increased Prevalence of Diabetes, Improved Survival Following Myocardial Infarction and Stroke, and U.S. Population Growth in 1991 (Bars)

ESRD, end-stage renal disease.

Line graphs showing absolute incident of E S R D has increased from near 0 in 1978 to almost 37,000 in 1991, with diabetes being the biggest contributor to this increase

SOURCE: Reference 310, copyright © 2003 American Society of Nephrology, reprinted with permission

TABLE 22.16 Prevalence of Reported End-Stage Renal Disease, by Primary Diagnosis, Sex, and Race/Ethnicity, U.S., 2008–2012

PRIMARY DISEASE GROUP | TOTAL PERSONS | INCIDENCE (%) | MEDIAN AGE (YEARS) | PERCENT
PRIMARY DISEASE GROUP | TOTAL PERSONS | INCIDENCE (%) | MEDIAN AGE (YEARS) | Male | White | Black/Af Am | Am Indian | Asian | Hispanic
All ESRD (reference) | 636,905 | 100 | 60 | 57.1 | 60.2 | 31.5 | 1.3 | 5.6 | 16.7
Diabetes | 239,837 | 39.3 | 63 | 55.8 | 60.8 | 30.6 | 2.1 | 5.9 | 22
Diabetes with renal manifestations, type 2 | 207,145 | 33.9 | 64 | 55.6 | 58.8 | 31.8 | 2.3 | 6.4 | 23.3
Diabetes with renal manifestations, type 1 | 32,692 | 5.4 | 51 | 56.7 | 73 | 22.5 | 1 | 2.7 | 13.6
Glomerulonephritis | 85,844 | 14.1 | 53 | 60.8 | 63.8 | 25.3 | 1.2 | 8 | 15.6
Secondary GN/vasculitis | 20,059 | 3.3 | 48 | 29.5 | 59.8 | 32.5 | 1 | 5.5 | 17.6
Interstitial nephritis/pyelonephritis | 22,562 | 3.7 | 59 | 54.5 | 80.5 | 13.3 | 0.7 | 4.4 | 10.9
Hypertensive/large vessel disease | 159,049 | 26 | 63 | 59.8 | 46.7 | 46.9 | 0.5 | 5.1 | 12.6
Cystic/hereditary/congenital diseases | 44,042 | 7.2 | 54 | 58.1 | 82.4 | 12.8 | 0.7 | 3 | 12.2
Neoplasms/tumors | 5,856 | 1 | 67 | 62.8 | 76.9 | 19.7 | 0.7 | 2.3 | 9.9
Complications of transplanted organ | 3,464 | 0.6 | 56 | 60.9 | 77.7 | 16.9 | 0.6 | 4.6 | 14.5

Data include persons alive on December 31, 2012. Af Am, African American; Am Indian, American Indian; ESRD, end-stage renal disease; GN, glomerulonephritis.

SOURCE: Reference 1

### Incidence of Diabetic ESRD

In 1985, the adjusted incidence of treated ESRD attributable to diabetes was 45 cases per million population. The rate increased to 170 per million by 2005 and leveled off thereafter (Table 22.17) (1). The increasing prevalence of diabetes and more inclusive criteria for initiating renal replacement therapy contributed to higher incidence rates of diabetes-related ESRD over time. Trends in the incidence of treated ESRD due to diabetes differ broadly by age and race/ethnicity. In whites, the sex-adjusted incidence rate of ESRD declined between 2000 and 2010 by 17%, 1%, and 3.6% in those ages 20–29, 30–39, and 60–69 years, respectively, and increased 29% in those age ≥70 years. In African Americans, by contrast, the incidence rate of ESRD, which is about fourfold higher than in whites, declined by 17% in those age 60–69 years only, and increased by 16%, 69%, and 10% in those ages 20–29, 30–39, and ≥70 years, respectively (Figure 22.27) (1). Incident ESRD due to diabetes also increased among young American Indians, Hispanics, and Asians, while declining in the older age groups. Racial differences in the incidence of treated ESRD in persons with type 2 diabetes are attributable in part to differences in the duration of diabetes, as American Indians, African Americans, and Asians generally develop diabetes at earlier average ages than do whites (311,312,313,314,315,316,317,318). A shift towards a younger age at onset of type 2 diabetes among some minority populations may be partly responsible for the secular trends in ESRD incidence observed in the younger groups, as illustrated by the Pima Indians (319,320). Whereas the incidence of diabetic ESRD in Pima Indians age ≥45 years declined after 1990, those age <45 years experienced no such decline. The lack of decline in the younger Pima Indians was associated with a lower percentage of RAAS inhibitor usage than in older subjects. Women of childbearing age were least likely to receive RAAS inhibitors, presumably because of concerns about their use in pregnancy. At the national level, the incidence of ESRD in persons with a primary diagnosis of diabetes remains higher in African Americans, Mexican Americans, Asians, and American Indians than in whites, with the highest rates being found in African Americans and American Indians.

Epidemiologic data on racial/ethnic differences in the incidence of treated ESRD in type 1 diabetes are sparse, in part because type 1 diabetes is less frequent, particularly among minority populations, and in part due to uncertainties related to diagnosis; young persons or those who are treated with insulin are often misclassified as having type 1 diabetes. According to USRDS data, of all new cases of treated ESRD due to diabetes between 2008 and 2012, 91% were attributable to type 2 diabetes (Table 22.18) (1).

### Survival of Persons With Diabetic ESRD

Persons with CKD who progress to ESRD receive renal replacement therapy, including hemodialysis, peritoneal dialysis, or kidney transplant, in order to survive. Those with a primary diagnosis of diabetes have lower survival relative to other causes of ESRD (1), primarily because of the coexistent morbidity associated with diabetes, particularly cardiovascular diseases (321,322,323,324), which continue to advance during the course of renal replacement therapy. One- and five-year survival rates in persons with diabetic ESRD are presented by age, sex, race/ethnicity, and primary diagnosis in Appendices 22.1 and 22.2 (1). While survival on dialysis has slowly improved across modalities since the 1990s (Figure 22.28), it remains reduced in persons with diabetes, half of whom die within 3 years of beginning dialysis in the United States (Appendix 22.3) (1). Among incident ESRD patients with a primary diagnosis of type 1 diabetes, first-year mortality declined from 13% in 2001–2005 to 8% in 2006–2010, while the proportion of first-year kidney transplants remained stable at 8% (1).

TABLE 22.17 Incidence Rates of Reported End-Stage Renal Disease Due to Diabetes, by Age, Sex, and Race/Ethnicity, 1985–2012

CHARACTERISTICS | INCIDENCE
CHARACTERISTICS | 1985 | 1990 | 1995 | 2000 | 2005 | 2010 | 2012
Crude | 35.1 | 70.5 | 107.5 | 143.4 | 154.9 | 161.7 | 156.9
Adjusted | 45.0 | 88.5 | 133.5 | 169.8 | 170.2 | 164.2 | 154.3
Age (years)^*^
0–19 | 0.1 | 0.2 | 0.1 | 0.1 | ^†^ | 0.1 | 0.1
20–44 | 25.1 | 33.6 | 36.0 | 36.9 | 37.9 | 43.3 | 41.2
45–64 | 104.5 | 203.9 | 294.7 | 340.9 | 325.5 | 298.6 | 286.3
65–74 | 135.0 | 321.5 | 553.4 | 745.4 | 719.8 | 675.8 | 614.9
≥75 | 51.7 | 141.2 | 293.9 | 528.3 | 596.6 | 619.1 | 556.1
Sex
Men | 46.9 | 88.9 | 136.0 | 184.1 | 198.6 | 198.4 | 187.7
Women | 43.0 | 87.7 | 131.0 | 157.5 | 146.4 | 135.5 | 125.8
Race
White | 30.3 | 61.2 | 90.9 | 122.3 | 128.8 | 127.5 | 122.1
Black/Af Am | 126.7 | 260.5 | 400.1 | 469.8 | 466.9 | 428.4 | 381.9
American Indian | 209.2 | 416.8 | 572.4 | 804.1 | 374.9 | 307.9 | 278.6
Asian | 77.6 | 106.2 | 190.6 | 220.0 | 197.3 | 197.0 | 189.1
Ethnicity^‡^
Hispanic | | | | 370.0 | 340.3 | 336.7 | 303.8
Non-Hispanic | | | | 149.6 | 153.9 | 147.7 | 140.0

Incidence rates are new cases per million population. Rates by age are adjusted for sex and race, rates by sex are adjusted for age and race, and rates by race/ethnicity are adjusted for sex and age. Persons of unknown age or sex, or of other or unknown race, are excluded. Af Am, African American; ESRD, end-stage renal disease.

* The age as of the date of ESRD initiation.

† Values for cells with 10 or fewer persons are suppressed.

‡ The Centers for Medicare and Medicaid Services began collecting Hispanic ethnicity data in April 1995.

SOURCE: Reference 1

FIGURE 22.27 Sex-Adjusted Incident Rates of End-Stage Renal Disease Due to Diabetes, by Age (Years) and Race/Ethnicity, U.S., 1980–2012

Rates are 3-year rolling averages. Data are standardized to the 2011 U.S. population. Af Am, African American; Hisp, Hispanic.

Line graphs showing the incident rate of E S R D increased more in blacks than whites between 1982 and 2012, while remaining stable in Hispanics from 1996 to 2012

SOURCE: Reference 1

TABLE 22.18 Incidence of Reported End-Stage Renal Disease, by Primary Diagnosis, Sex, and Race/Ethnicity, U.S., 2008–2012

PRIMARY DISEASE GROUP | TOTAL PERSONS | INCIDENCE (%) | MEDIAN AGE (YEARS) | PERCENT
PRIMARY DISEASE GROUP | TOTAL PERSONS | INCIDENCE (%) | MEDIAN AGE (YEARS) | Male | White | Black/Af Am | Am Indian | Asian | Hispanic
All ESRD (reference) | 570,481 | 100 | 64 | 57 | 66 | 28 | 1.1 | 4.7 | 14.5
Diabetes | 252,165 | 45.9 | 63 | 55.4 | 65.7 | 27.1 | 1.7 | 5.3 | 19.7
Diabetes with renal manifestations, type 2 | 230,536 | 42 | 64 | 55.4 | 65.3 | 27.3 | 1.8 | 5.5 | 20.2
Diabetes with renal manifestations, type 1 | 21,629 | 3.9 | 51 | 55.9 | 70 | 25.7 | 1.1 | 3.1 | 15
Glomerulonephritis | 35,787 | 6.5 | 55 | 61.5 | 68.2 | 23.4 | 1.1 | 7.1 | 13.3
Secondary GN/vasculitis | 11,254 | 2 | 50 | 33.9 | 64 | 30.4 | 1 | 4.4 | 14.9
Interstitial nephritis/pyelonephritis | 16,340 | 3 | 65 | 58.6 | 82.9 | 13.1 | 0.6 | 3.3 | 8.4
Hypertensive/large vessel disease | 160,891 | 29.3 | 69 | 58.2 | 59.2 | 36.2 | 0.4 | 4 | 9.9
Cystic/hereditary/congenital diseases | 17,720 | 3.2 | 51 | 57 | 81.9 | 14 | 0.6 | 3.3 | 11.9
Neoplasms/tumors | 11,160 | 2 | 69 | 64.1 | 79.4 | 17.9 | 0.6 | 1.9 | 7.8
Complications of transplanted organ | 2,308 | 0.4 | 59 | 65.2 | 83.5 | 12.4 | 0.6 | 3.2 | 8.3

Af Am, African American; Am Indian, American Indian; ESRD, end-stage renal disease; GN, glomerulonephritis.

SOURCE: Reference 1

African Americans (325,326), Hispanics (327), Asians (1), and American Indians (1,328) treated for diabetic ESRD have a lower risk of death compared with whites (Appendix 22.4) (1). Among patients on hemodialysis due to diabetic kidney disease, the risk of death was 31% lower in American Indian, African American, or Hispanic patients compared with whites and 38% lower in Asians. Among American Indians, those with full Indian blood ancestry had the lowest adjusted risk of death compared with whites (HR 0.58, 95% CI 0.55–0.61) (Figure 22.29) (284). The risk of death increased to 0.95 (95% CI 0.82–1.11) in those with less than one-quarter American Indian ancestry (284), suggesting that hereditary factors play a role in how patients respond to dialysis treatment. Similarly, a study conducted in white, African American, and Hispanic incident dialysis patients between 1995 and 2009 showed lowest mortality risk in Hispanics, intermediate in African Americans, and highest in non-Hispanic whites (326). Although patients with diabetes were not analyzed separately, the survival advantage persisted in older patients who were more likely to have diabetes as a cause of ESRD. Similar to persons with ESRD in general, the leading causes of death among adults with diabetes who started dialysis in 1995–2009 were CVD, representing 58% of the deaths, and infections, representing 13% of the deaths; malignancy accounted for 3% and withdrawal from dialysis for 5% of the deaths. Nonetheless, the adjusted annual death rate in patients with diabetes as a primary cause of ESRD improved steadily since 1985, more so than among patients with other causes of ESRD (Appendix 22.5) (1).

FIGURE 22.28 Five- and Ten-Year Survival for Incident Persons With Diabetes, by End-Stage Renal Disease Treatment Modality, U.S., 1985–2007

Adjusted for age, sex, race, and primary diagnosis. Reference cohort is 2011 incident ESRD population. HD and CAPD/CCPD survival censored at transplant. CAPD/CCPD, continuous ambulatory peritoneal dialysis/continuous cycler peritoneal dialysis; ESRD, end-stage renal disease; HD, hemodialysis; Tx, kidney transplant.

Line graph showing that 5 and 10 year survival after E S R D diagnosis increased from 1985 to 2007 and is higher for those receiving a transplant than dialysis

SOURCE: Reference 1

Kidney transplant recipients with diabetes have much better survival than those on dialysis, as shown in Figure 22.28 (1). In 2012, the adjusted death rate in those with diabetes-related kidney transplant was 45 cases per 1,000 person-years at risk, significantly lower than the 186 cases per 1,000 person-years among those on dialysis, and lower even than the 88 cases per 1,000 person-years among those on the waiting list for kidney transplant, although the transplant candidates are presumably similar in other respects to those who receive transplants (329,330). The lifespan increase after kidney transplant was greater among persons with ESRD due to diabetes than to other causes (331), indicating a significant impact of the type of renal replacement therapy (transplant versus dialysis) on long-term survival.

FIGURE 22.29 Hazard Ratios for Death From Any Cause Among Non-Hispanic American Indians With Diabetes at Initiation of Hemodialysis, by Degree of American Indian Ancestry

Information on American Indian ancestry was obtained from the IHS patient database. The reference group is non-Hispanic whites on hemodialysis with a primary diagnosis of diabetes (dashed horizontal line). The capped vertical lines represent 95% confidence intervals around the hazard ratio estimates. Hazard ratios are adjusted for sex, age, body mass index, estimated glomerular filtration rate, current smoking status, erythropoietin treatment, history of hypertension, cardiovascular disease, chronic obstructive pulmonary disease, or malignancy. AI/AN, American Indian/Alaska Native; HR, hazard ratio; IHS, Indian Health Service.

Plot showing hazard ratios of death after dialysis initiation was lower in those with a greater degree of American Indian ancestry compared to non-Hispanic whites

SOURCE: Reference 284, copyright © 2014 American Public Health Association, reprinted with permission

## Risk Factors for Diabetic Kidney Disease

Numerous risk factors have been identified for the development and progression of diabetic kidney disease. In this section, the evidence for some of the more prominent factors is reviewed.

### Duration of Diabetes

One of the most important risk factors for diabetic kidney disease is the duration of diabetes, its influence being far greater than that of age, sex, or type of diabetes. For a given duration of diabetes, the cumulative incidences of overt nephropathy and ESRD are similar in type 1 and type 2 diabetes (309,312,332,333,334).

### Socioeconomic Factors

Socioeconomic factors are often taken into consideration when describing associations between risk factors and CKD in large populations with diabetes. A low socioeconomic status is associated with increased prevalence of diabetes, hypertension, and CKD (335,336,337). The mechanism of this association, however, is unclear and often difficult to separate from racial/ethnic predisposition or other environmental factors. Exposure to an adverse prenatal environment, such as that caused by poor maternal dietary habits, smoking, or poor health, may also introduce adverse health traits that persist in subsequent generations (338).

### Hyperglycemia

Increased blood glucose concentration is a major risk factor for the development and progression of moderate albuminuria in both types of diabetes (93,232,235,236,237,238,332,339,340,341,342,343,344,345,346,347,348,349,350,351) but may have a lesser influence on progression of more advanced kidney dysfunction (341,352), when hypertension, hypercholesterolemia, and genetic factors play a greater role in shaping the outcome (36,340). The relative risk of developing proteinuria (≥0.30 g/L) after 4 years in subjects with type 1 diabetes in Wisconsin was three times as high for those with A1c in the highest quartile compared with those in the lowest quartile (Figure 22.30) (233). Similarly, in the EDC study, participants with type 1 diabetes and A1c >10% (>86 mmol/mol) had a 3.6-fold higher risk to develop moderate albuminuria than those with lower A1c levels. Glycemic control was the only predictor of moderate albuminuria in both men and women, regardless of diabetes duration (340). Higher 2-hour postload plasma glucose concentration, fasting plasma glucose, and A1c in Pima Indians with type 2 diabetes were associated with a higher incidence of elevated ACR after adjustment for age, sex, and duration of diabetes (Figure 22.31) (238,342). Similarly, among American Indians age 45–74 years with type 2 diabetes from Arizona, Oklahoma, and North and South Dakota, higher fasting plasma glucose and A1c among those with normal baseline ACR and serum creatinine were associated with increased risk of elevated albuminuria (258).

Hyperglycemia induces hyperfiltration, a predictor of progressive kidney disease (59,60,61,353,354). In diabetic rats, normalization of blood glucose levels reverses hyperfiltration (355), and insulin infusion reduces the glomerular capillary hydraulic pressure (86). In humans, therapeutic interventions that improve glycemic control reduce hyperfiltration in both type 1 and type 2 diabetes (86,356). Persistent hyperglycemia also causes dysregulation of a number of effector molecules through several biochemical pathways in the kidney, including generation and accumulation of advanced glycation endproducts, increased activity of the polyol pathway, and activation of vasoactive hormones, such as angiotensin II and endothelin (357,358,359). Activated prosclerotic cytokines, such as transforming growth factor beta (TGF-β) and vascular endothelial growth factor (VEGF), are important mediators between metabolic and hemodynamic pathways leading to pathologic changes of the glomerular filtration barrier (Figure 22.32) (357).

Further evidence for the role of hyperglycemia in the development of diabetic glomerular lesions comes from biopsy studies in identical twins discordant for type 1 diabetes (360) and from morphologic studies before and after pancreas transplantation (361). Glomerular changes, including widened glomerular and tubular basement membranes and increased mesangial fraction, were identified only in the diabetic member of twin pairs (Figure 22.33), suggesting that metabolic status, and not genetic predisposition, is responsible for the development of diabetic kidney lesions (360). Prolonged normoglycemia following pancreas transplant in persons with type 1 diabetes and established diabetic kidney disease promotes virtually complete reversal of glomerular and tubular basement membrane thickness and of increases in mesangial and interstitial volumes (Figure 22.34) (361).

### Hypertension

High blood pressure is related to diabetic kidney disease in many cross-sectional and longitudinal studies of both type 1 and type 2 diabetes. In type 1 diabetes, this relationship frequently reflects elevation of blood pressure in response to kidney disease (362,363,364,365); whereas in type 2 diabetes, the onset of hypertension generally precedes diabetic kidney disease and is often associated with obesity. The risk of kidney disease is three times as high in persons with type 1 diabetes who have a hypertensive parent as in those whose parents are not hypertensive (Figure 22.35) (366). In addition, those with kidney disease have a higher prevalence of parental hypertension and a higher mean arterial blood pressure during adolescence (367). Increased blood pressure during sleep may herald the development of moderate albuminuria in adolescents and young adults with type 1 diabetes, as shown in Figure 22.36 (368). In that study, blood pressure was monitored at 2-year intervals for up to 9 years or as long as the ACR was in the normal range; a ratio of ≤0.9 between the mean nighttime systolic pressure and the mean daytime systolic pressure defined the dipping during sleep. Moderate albuminuria did not develop in those with poor metabolic control in whom blood pressure remained normal, suggesting that nocturnal elevation in blood pressure may identify those with type 1 diabetes who are most susceptible to progression of kidney disease.

FIGURE 22.30 Four-Year Incidence of Proteinuria in Type 1 Diabetes, By Glycosylated Hemoglobin (A1c) Level, Wisconsin, 1980–1986

Proteinuria is defined as urinary protein excretion ≥0.30 g/L, determined by reagent strip. Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions.

Bar graph showing the 4 year incidence of proteinuria in people with type 1 diabetes was higher among those with higher levels of A1c

SOURCE: Reference 233

FIGURE 22.31 Incidence of Proteinuria in Pima Indians With Type 2 Diabetes, by OGTT Glucose Level and Diabetes Duration

Incidence of proteinuria (protein-to-creatinine ratio ≥1.0 g/g) by duration of diabetes in 480 Pima Indians with type 2 diabetes, according to tertiles of 2-hour plasma glucose concentration after 75 g oral glucose, measured at diagnosis of diabetes. Conversions for glucose values are provided in Diabetes in America Appendix 1 Conversions. OGTT, 2-hour oral glucose tolerance test.

Line graph showing that higher levels of 2-hour glucose at diagnosis and longer duration of diabetes was associated with higher incidence of proteinuria

SOURCE: Reference 238, copyright © 1989 Elsevier, reprinted with permission

In Pima Indian offspring with type 2 diabetes, the prevalence of proteinuria was similar if neither parent or only one parent had hypertension (8.9% and 9.4%, respectively) but was significantly higher if both parents had hypertension (18.8%), after adjustment for age, sex, duration of diabetes, and 2-hour postload plasma glucose concentration in the offspring and diabetes in the parents (369). The odds for proteinuria in the offspring when both parents had hypertension was 2.2 times (95% CI 1.2–4.2) that when only one parent had hypertension. This relationship was present even when controlled for the effects of blood pressure and its treatment in the offspring. In addition, higher blood pressure before the onset of type 2 diabetes was related to a higher prevalence of elevated albuminuria after the onset of diabetes, suggesting that blood pressure plays a causal role in the development of diabetic kidney disease (Figure 22.37) (370).

Sodium-lithium countertransport activity, a genetically influenced trait, is often higher in persons with essential hypertension and in those whose parents have essential hypertension (371,372,373,374). In type 1 diabetes, elevated rates of countertransport activity are reported in persons with moderate albuminuria or proteinuria (Figure 22.38) (375,376,377,378), elevated GFR (379), and proliferative retinopathy (380). These findings suggest that diabetic persons with hypertension and with elevated sodium-lithium countertransport activity are at greater risk for CKD and possibly other microvascular complications, although these findings have not been uniformly confirmed (378,381,382). Few studies assessed this relationship in those with type 2 diabetes; some found an association between higher sodium-lithium countertransport activity and albumin-uria (383,384,385), and others did not (386,387).

### Lipids

Many of the abnormalities in plasma lipoproteins associated with kidney disease are sequelae of kidney dysfunction, yet dyslipidemia may also play a role in the pathogenesis of glomerular injury (388,389,390). Persons with diabetes and predialysis CKD typically have significant hypertriglyceridemia, elevated LDL, and low high-density lipoprotein (HDL) cholesterol levels. These abnormalities are more pronounced in persons with severe albuminuria than those with moderate albuminuria (33,391,392,393) but tend to subside with progression to uremia and dialysis (Table 22.19) (394). Besides quantitative changes, lipid particles in people with diabetes change qualitatively; LDL and HDL particles tending to be smaller and denser with advancing CKD (393,395).

FIGURE 22.32 Pathways for Potential Interactions Between Glucose Metabolism and Hemodynamic Factors Leading to Diabetic Nephropathy

PKC, protein kinase C; TGF-β, transforming growth factor beta; VEGF, vascular endothelial growth factor.

Flow chart showing activated pro-sclerotic cytokines are important mediators between metabolic and hemodynamic pathways leading to proteinuria

SOURCE: Reference 357, reprinted from The Lancet copyright © 1998, with permission from Elsevier

In type 1 diabetes, LDL cholesterol predicted progression of diabetic kidney disease as defined by a doubling of albuminuria or a decline in creatinine clearance in excess of 3 mL/min/year (396). In that study, LDL cholesterol was associated with elevated albuminuria after nearly 9 years of follow-up; a higher triglyceride content of very low-density lipoprotein (VLDL) and intermediate-density lipoprotein (IDL) particles predicted worsening of moderate albuminuria, whereas smaller LDL size was associated with declining kidney function in persons with severe baseline albuminuria. These findings suggest that specific lipids or lipid profiles may influence the onset or progression of diabetic kidney disease, although these findings have not been consistently observed (340,397,398,399).

In type 2 diabetes, prospective studies with long follow-up found that LDL cholesterol increases the risk for severe albuminuria (400) and ESRD (401). In a post hoc analysis of 1,061 persons with type 2 diabetes included in the Reduction of Endpoints in Non-insulin dependent diabetes with the Angiotensin II Antagonist Losartan (RENAAL) study, the risk of ESRD was 32% higher for each 50 mg/dL (1.30 mmol/L) increase in LDL cholesterol concentration and 67% higher for each 100 mg/dL (2.59 mmol/L) increase in total cholesterol concentration; lowering LDL cholesterol concentrations with a statin reduced the 1-year risk of ESRD, although concurrent treatment with losartan, an angiotensin receptor blocker (ARB), likely contributed to improving this outcome by reducing both lipid levels and ACR (401). Elevated plasma triglycerides are associated with increased risk for both moderate and severe albuminuria (400) and with ESRD in type 2 diabetes (402). In addition, low concentrations of HDL cholesterol predict increased risk of albuminuria progression in persons with type 2 diabetes and moderate albuminuria (403,404). In the UKPDS, each mmol/L decline in HDL cholesterol increased the risk of doubling of serum creatinine concentration nearly threefold (HR 2.78, 95% CI 1.01–7.68) 15 years after the diagnosis of type 2 diabetes (400). The Strong Heart Study examined the relationship between plasma lipoprotein concentrations and the risk of elevated albuminuria (ACR ≥30 mg/g) in 671 American Indians with type 2 diabetes who were followed for a mean of 3.9 years (405). At baseline, small LDL (particle size <254 Å, measured by gradient gel electrophoresis) was present in 38% men and 25% women, and large LDL (particle size ≥257 Å) was present in 50% men and 61% women. A low HDL cholesterol concentration was associated with elevated ACR in women only (OR 0.56, 95% CI 0.32–0.98) after adjustment for age, duration of diabetes, hypoglycaemic treatment, A1c, study site, degree of Indian heritage, mean arterial blood pressure, baseline albumin excretion, insulin concentration, BMI, alcohol consumption, and physical activity. The association between HDL cholesterol and increased ACR in women was largely explained by a HDL cholesterol concentration <0.9 mmol/L, with little additional effect at higher HDL concentrations (Figure 22.39) (405). No other lipids were found to increase the risk of incident albuminuria; high levels of total and VLDL triglycerides and small LDL size were positively, but not significantly, associated with abnormal albuminuria. In the absence of a standard measure of insulin resistance, however, the study could not determine whether low HDL cholesterol itself, insulin resistance, or other correlated variables are most prominently increasing the risk of nephropathy (405).

FIGURE 22.33 Morphometric Measurements in Kidney and Skeletal Muscle From Identical Twins Discordant for Type 1 Diabetes

(A) Basement membrane width (nm) and (B) fractional volume of the mesangium (%). Values for twins without diabetes (●) are linked to values for their siblings with diabetes (○). The numbers next to the lines indicate the twin pair. The shaded areas indicate normal ranges. The normal range for glomerular basement membrane in men (higher normal values) overlaps the range in women (lower normal values). Significant differences between siblings with diabetes and their twins without diabetes were found for glomerular basement membrane width (p=0.002), tubular basement membrane width (p=0.0012), and fractional volume of the mesangium (p=0.0035), but not muscle capillary basement membrane width (p=0.50).

Line graphs showing widened glomerular and tubular basement membranes and increased mesangial fraction in those with diabetes compared to an identical twin without diabetes

SOURCE: Reference 360, copyright © 1985 Massachusetts Medical Society, reprinted with permission

FIGURE 22.34 Renal Histologic Changes at Baseline and 5 and 10 Years After Pancreas Transplantation

(A) Thickness of the GBM, (B) thickness of TBM, (C) mesangial fractional volume, and (D) mesangial matrix fractional volume are shown before (baseline) and after pancreas transplantation. Shaded areas represent the normal ranges obtained in 66 age- and sex-matched normal controls (mean±2 standard deviations). GBM, glomerular basement membrane; Mes, mesangium; MM, mesangial matrix; TBM, tubular basement membrane; Vv, fractional volume.

Line graphs showing decreases in G B M thickness, T B M thickness, mesangial fractional volume, and mesangial matrix fractional volume 10 years after pancreas transplantation

SOURCE: Reference 361, copyright © 2012 Springer, reprinted with permission

Dyslipidemia might contribute to onset and progression of diabetic kidney disease through mechanisms similar to those responsible for arterial atherogenesis (389,406,407). The diabetic environment facilitates glomerular production of triglycerides and cholesterol, which appear to cause kidney injury both directly by accumulating in the cellular and extracellular structures and indirectly by stimulating the expression of prosclerotic, proliferative, and proinflammatory cytokines (85,390,406). Hypercholesterolemia may impair the kidney’s hemodynamic responses and tubular function by decreasing nitric oxide production and/or increasing superoxide activity in the kidney (408,409,410,411,412), with resulting antidiuretic and antinatriuretic effects (413). Although not directly affecting GFR, these actions may play a role in the development of systemic hypertension associated with diabetes (413). Oxidized LDL and free fatty acids can cause structural and functional damage to podocytes by inducing mitochondrial dysfunction and accumulation of reactive oxygen species (414), suggesting a direct causal role in the development and progression of proteinuria. Experimental rodent models of type 1 and type 2 diabetes indicate that down-regulation of glomerular ATP-binding cassette transporter (ABCA1) expression can lead to excessive cholesterol accumulation in podocytes (415,416). Under normal conditions, ABCA1 mediates the efflux of cholesterol to lipid-poor apolipoproteins (primarily Apo A1) to form HDLs. This mechanism has also been demonstrated in glomerular transcripts from persons with diabetic kidney disease when compared with living normal controls (417,418). Nevertheless, a definitive role for dyslipidemia in the development and progression of diabetic kidney disease in humans remains to be established.

FIGURE 22.35 Mean Blood Pressure in Parents of Persons With Type 1 Diabetes and With or Without Proteinuria

Family study of diabetes, including 26 surviving parents of 17 persons with type 1 diabetes and proteinuria and parents of 17 matched persons without diabetes or proteinuria. Figure shows mean blood pressure in the parent with higher arterial pressure of 17 proteinuric and 17 nonproteinuric diabetic persons; horizontal lines are means. Mean blood pressure of parents of proteinuric subjects averaged 11 mmHg (95% confidence interval 1.7–20.3 mmHg) higher than in parents of diabetic subjects without proteinuria. Proteinuria is defined as urinary protein >0.15 g/L.

Dot plot showing higher blood pressure in parents of type 1 diabetes patients with proteinuria compared to parents of those without proteinuria

SOURCE: Reference 366, copyright © 1987 BMJ Publishing Group, reprinted with permission

FIGURE 22.36 Nocturnal Systolic Blood Pressure According to Albuminuria and Level of Glycosylated Hemoglobin (HbA_1c_) in Type 1 Diabetes

(A) Nocturnal systolic pressure in 14 subjects who subsequently developed moderate albuminuria (microalbuminuria) and in 61 subjects who remained normoalbuminuric. (B) Nocturnal systolic blood pressure according to the mean (±standard deviation) HbA_1c_. The final evaluation was the last evaluation during follow-up in the normoalbuminuria group or the last evaluation before the development of moderate albuminuria. Vertical bars indicate standard deviations. Microalbuminuria was defined as albumin excretion of 30–299 mg/24 hours, in two consecutive measurements less than 6 months apart. Conversions for HbA_1c_ values are provided in Diabetes in America Appendix 1 Conversions. HbA_1c_, glycosylated hemoglobin.

Line graph showing an increase in nocturnal systolic blood pressure was observed in those who developed albuminuria but not those who did not develop albuminuria, regardless of A1c level

SOURCE: Reference 368, copyright © 2002 Massachusetts Medical Society, reprinted with permission

### Dietary Protein

In epidemiologic studies, higher-protein diets are associated with development of diabetes, as well as with greater risk of kidney damage or loss of function, especially in individuals with diabetes, hypertension, and/or reduced kidney function. These risks are mainly confined to animal meat intake. Vegetable or dairy proteins do not appear to adversely affect kidney health (419,420).

In experimental models, excessive protein intake causes kidney vasodilation and glomerular hyperperfusion with a resulting increase in the intraglomerular pressure that leads to proteinuria and glomerular damage (421,422). In addition, long-term high protein intake accelerates structural and functional injury in models of diabetic kidney disease, whereas low-protein diets offer kidney protection (423,424,425,426,427,428). Physiologic studies in humans confirm the hyperfiltration response found in animal studies, but only in the presence of chronic hyperglycemia (429,430). On the other hand, dietary protein of animal origin may be a significant source of advanced glycation endproducts, particularly when cooked at high temperatures or in fat (431). In vitro studies indicate that advanced glycation endproducts can produce kidney damage through a variety of mechanisms even from the very early stages of kidney disease, but their contribution to disease progression is still unclear. Two other studies explored the association between CKD and dietary acid load, a surrogate for the intake of acid-inducing foods (rich in animal proteins) versus base-inducing foods (fruits and vegetables), quantified as the net acid excretion estimated from 24-hour dietary recall (432), and between CKD and metabolic acidosis (433). The former found that higher dietary acid load among 12,293 U.S. adult participants in the NHANES 1999–2004 was associated with eGFR <60 mL/min/1.73 m^2^ or elevated albuminuria in participants with hypertension and in those without hypertension or diabetes. Older age, poverty, black race, and male sex, but not diabetes, were significantly associated with an increasing level of net acid excretion in this population. In the latter study (including 21% persons with diabetes), serum bicarbonate level ≤22 mEq/L was associated with a 54% higher risk of eGFR decline during a median follow-up of 3.4 years after adjustment for baseline eGFR and clinical, demographic, and socioeconomic patient characteristics. Since this study had no information on patients’ diet or medication during the follow-up, the findings cannot be attributed directly to dietary protein intake.

FIGURE 22.37 Prevalence of Elevated Albuminuria in Pima Indians After Diagnosis of Type 2 Diabetes, by Blood Pressure Before Onset of Diabetes

Elevated albuminuria is defined by urinary albumin-to-creatinine ratio ≥100 mg/g. Participants with the highest prediabetic blood pressure had the highest prevalence of elevated albuminuria after onset of diabetes.

Bar graph showing albuminuria after diabetes diagnosis was more common in those who had higher mean blood pressure before diabetes diagnosis

SOURCE: Reference 370

FIGURE 22.38 Correlation of Sodium-Lithium Countertransport Activity With Nephropathy

Sodium-lithium (Na-Li) countertransport activity measured in 21 persons with type 1 diabetes and normoalbuminuric matched controls. Diabetic nephropathy is defined by a urinary protein excretion >0.5 g/24 hours. The horizontal bars represent medians.

* p=0.02

Dot plot showing sodium-lithium counter-transport activity was higher with albuminuria than those with normoalbuminuria

SOURCE: Reference 375, copyright © 2004 American Society of Nephrology, reprinted with permission

Thus, although a theoretical case can be made for the impact of dietary protein on the development of diabetic kidney disease, no observational data in humans unequivocally support such a role.

### Smoking

A cross-sectional analysis of 61,675 participants in the NKF’s Kidney Early Evaluation Program (KEEP), 27.1% of whom had CKD, identified smoking along with obesity, diabetes, hypertension, and CVD as significant factors associated with CKD (434). Similarly, in 14,632 participants in the NHANES 1999–2004, 15.3% of whom had CKD, current smoking increased the odds of CKD by 31% (434).

TABLE 22.19 Changes in Lipids, Lipoproteins, Apo A, and Apo B, by Stages of Chronic Kidney Disease

LIPID PARAMETER | CKD 1–5 | NEPHROTIC SYNDROME | HEMODIALYSIS | PERITONEAL DIALYSIS
Total cholesterol | ↗ | ↑↑ | ↔↓ | ↑
LDL cholesterol | ↗ | ↑↑ | ↔↓ | ↑
HDL cholesterol | ↓ | ↓ | ↓ | ↓
Non-HDL cholesterol | ↗ | ↑↑ | ↔↓ | ↑
Triglycerides | ↗ | ↑↑ | ↑ | ↑
Lp(a) | ↗ | ↑↑ | ↑ | ↑↑
Apo A-I | ↘ | ↗ | ↓ | ↓
Apo A-IV | ↗ | ↑↘ | ↑ | ↑
Apo B | ↗ | ↑↑ | ↔↓ | ↑

Changes derived from the combined literature. Non-HDL cholesterol includes cholesterol in LDL, VLDL, intermediate density lipoprotein, and chylomicron and its remnant. Normal (↔), increased (↑), markedly increased (↑↑), and decreased (↓) plasma levels compared with non-uremic individuals; increasing (↗) and decreasing (↘) plasma levels with decreasing GFR. Apo A, apolipoprotein A; Apo B, apolipoprotein B; CKD, chronic kidney disease; HDL, high-density lipoprotein; LDL, low-density lipoprotein; Lp, lipoprotein.

SOURCE: Reference 394, copyright © 2007 American Society of Nephrology, reprinted with permission

In a large population-based study, maternal smoking during pregnancy increased the odds of albuminuria in the full-term offspring who later developed type 1 diabetes by threefold, independent of low birth weight or blood pressure levels (435). In young persons with type 1 diabetes who smoked, the risk of albuminuria was nearly threefold higher than in nonsmokers (436). Likewise, the frequency of proteinuria (>500 mg/24 hours) was twice as high in smokers as in nonsmokers of similar age, duration of type 1 diabetes, A1c, and prevalence of hypertension (437). On the other hand, no relationship was observed between smoking and GFR decline in a longitudinal study of type 1 diabetic persons with albuminuria and serial ^51^Cr-EDTA GFR measurements over a median follow-up of 7 years (Figure 22.40) (438), although other smaller studies identified an association (439,440,441).

In men with type 2 diabetes, cigarette smoking was associated with higher A1c and ACR levels in a dose-dependent fashion (442), with nearly one-half of the heavy smokers having A1c >9% (>75 mmol/mol) and ACR ≥30 mg/g. The odds of elevated ACR were 2.8–3.2 times as high in those smoking more than 15 pack-years than in nonsmokers, regardless of age, blood pressure control, or diabetes duration (Figure 22.41). This and other studies in type 2 diabetes suggest that smoking is associated with kidney damage regardless of blood pressure control and treatment with RAAS inhibitors (443,444). Smoking also increased the risk of moderate or severe albuminuria (adjusted OR 1.50, 95% CI 1.21–1.86) after 5 years of follow-up in a large population-based study of persons with type 2 diabetes and no kidney disease at baseline from the Swedish National Diabetes Registry, although no association was found with the rate of kidney function decline (445).

FIGURE 22.39 Effect of Serum HDL Cholesterol Concentration on the Incidence of Albuminuria in American Indians With Type 2 Diabetes, Strong Heart Study, 1989–1996

Effect of HDL cholesterol concentration on the incidence of albuminuria (ACR ≥30 mg/g) in persons with diabetes and normal urinary albumin at baseline. Results are controlled for age, treatment with oral hypoglycemic agents or insulin, glycosylated hemoglobin (A1c), study site, degree of Indian heritage, mean arterial blood pressure, baseline albuminuria, and duration of diabetes at follow-up. A generalized additive logistic regression model was used so that non-linearity in the relation could be examined. In each sex, the p-value reflects a test for any effect (linear or not) of HDL cholesterol. Conversions for HDL cholesterol values are provided in Diabetes in America Appendix 1 Conversions. ACR, albumin-to-creatinine ratio; HDL, high-density lipoprotein.

Line graph showing low H D L levels were associated with greater albuminuria in women but not in men

SOURCE: Reference 405, copyright © 1998 Springer, reprinted with permission

Nicotine promotes the proliferation of mesangial cells and upregulates specific molecules involved in extracellular matrix production (446,447). In db/db mice, exposure to tobacco smoke for 8 weeks induces significant mesangial expansion and increases TGF-β and fibronectin expression compared with nonexposed mice (447). These changes, however, are not accompanied by significant changes in urinary albumin excretion. Experimental prenatal exposure to smoking results in neonates whose kidneys are proportionally smaller and exhibit reduced thickness of proximal tubule cuboidal epithelium, dysmorphia of the proximal and distal convoluted tubules, and immature glomeruli (448). In addition to nicotine, mainstream cigarette combustion produces over 4,000 compounds, including reactive oxygen species, carbon monoxide, nitric oxide, toxic metals, and polycyclic aromatic hydrocarbons, which may add to an already increased susceptibility to kidney disease in persons with diabetes (449). Although the precise mechanisms are unclear, tobacco smoking is known to cause vasoconstriction, impair platelet function and coagulation, and alter blood pressure (450,451). Given that persons with diabetes already have widespread vascular damage as a consequence of their diabetes (452), smoking may serve to accelerate the process.

FIGURE 22.40 Impact of Smoking Habit on Kidney Function, Adjusted for Difference in Blood Pressure Between Groups, Steno Clinic, 1983–1997

GFR was measured yearly by the ^51^Cr-EDTA plasma clearance technique. In 301 persons with type 1 diabetes and severe albuminuria followed for a median of 7 years (range 3–14 years), the mean GFR decline was 4.0 mL/min/year, with no difference between nonsmokers (n=94), ex-smokers (n=31), and smokers (n=176) (p=24). The adjusted rates of GFR decline were 4.1 mL/min/year in nonsmokers, 3.1 mL/min/year in ex-smokers, and 4.1 mL/min/year in the smoking group. Severe albuminuria is defined as persistent albuminuria ≥300 mg/24 hours in at least two of three consecutive urine collections, presence of diabetic retinopathy, and absence of any clinical or laboratory evidence of other kidney or renal tract disease. Error bars represent 95% confidence intervals. GFR, glomerular filtration rate.

Bar graph showing the decline in glomerular filtration rate was similar for smokers, ex-smokers, and nonsmokers after adjusting for blood pressure

SOURCE: Reference 438

### Obesity

Obesity is a major risk factor for diabetes, hypertension, and CVD, all of which increase the risk for kidney disease. It increasingly affects young people, particularly Hispanics, African Americans, and American Indians (453), leading to an earlier onset of diabetes and its major complications, including kidney disease (454). The longitudinal population-based study in the Pima Indians showed that between 1965 and 2003, BMI increased in all age groups, including children. During the same time period, the incidence of diabetes increased nearly sixfold among those age <15 years, without a similar trend in the older ages. These findings suggest that the increasing prevalence and degree of obesity in the youth combined with a nearly fourfold increase in the frequency of exposure to diabetes in utero have shifted the onset of diabetes to younger ages (455). For any diabetes duration, participants with youth-onset type 2 diabetes had a lower risk of ESRD (p=0.007) than those with older-onset diabetes. Because of the longer duration of diabetes by mid-life, however, the incidence of ESRD was higher between ages 25 and 54 years in those with youth-onset diabetes than in those with adult-onset diabetes (p<0.001) (Figure 22.42) (319). Given the continued increase in obesity, the experience in the Pima Indians may be relevant to other populations at high risk for diabetes.

Animal and human kidney biopsy studies describe obesity-associated adaptive increases in GFR and renal plasma flow, resulting from both proximal salt reabsorption and elevated angiotensin II, as well as structural changes, such as glomerular hypertrophy and focal segmental glomerulosclerosis (456). A retrospective clinical and histopathologic study of 6,818 native kidney biopsies found diabetes-like lesions in 45% of persons with obesity-related glomerulopathy (457). Further, the prevalence of obesity-related glomerulopathy, defined as glomerulomegaly with or without focal segmental glomerulosclerosis, increased tenfold over a 15-year period (from 0.2% in 1986–1990 to 2.0% in 1996–2000) (457). As the authors excluded other causes of focal segmental glomerulosclerosis, this increase was largely attributed to the rising prevalence of obesity in the general population. Notably, five individuals who lost significant weight experienced a 50%–75% decline in proteinuria, and their kidney function remained stable.

Leptin, a peptide hormone regulating appetite and body weight, is believed to play an essential role in obesity-related nephropathy, as suggested by several studies (458,459,460). Hyperleptinemia associated with excessive adipose tissue induces glomerular and tubular dysfunction through sympathetic nervous system activation, profibrotic, proliferative, and proinflammatory mechanisms (461). Moreover, kidney-specific leptin resistance induced by overeating exerts proliferative and profibrotic effects that contribute to impaired kidney function independently of systemic leptin levels and possibly induces progressive kidney dysfunction in advance of diabetes onset (461).

### Periodontal Disease

Periodontal disease, which often occurs in the absence of diabetes, is also a frequent complication of diabetes (462), contributing to poor glycemic control, low-grade chronic systemic inflammation, and increased risk of macro-vascular and microvascular complications (462,463,464). (See also Chapter 31 Oral Health and Diabetes.) Because diabetes is the leading cause of ESRD, periodontitis is frequently present among dialysis patients, increasing the risk for cardiovascular death (463,465). Severity of periodontitis and being edentulous predicted severe albuminuria and ESRD in a dose-dependent manner among adults with type 2 diabetes followed for a median of 9 years (466). A study investigating the relationships between diabetes, periodontal disease, and CKD in the NHANES 1988–1994 population suggested a bidirectional relationship between CKD and periodontal disease, with periodontitis increasing the risk of CKD both directly and mediated by hypertension and duration of diabetes, and CKD having a direct effect on periodontitis (467). Control of periodontal infection in diabetic adults improves A1c level (462) and reduces the concentration of various markers of inflammation, coagulation, and adhesion (468,469). Whether such control also reduces the onset or progression of diabetic kidney disease is not known.

FIGURE 22.41 Adjusted Odds Ratios of Albuminuria in Males With Type 2 Diabetes, Overall and by Age, Blood Pressure, Duration of Diabetes, and Smoking Habit, DMIDS Project, 2003–2007

The reference group, nonsmokers, is represented by the horizontal line. Study included males with type 2 diabetes in Taiwan enrolled in the Diabetes Management through Integrated Delivery System (DMIDS) project. The models are adjusted for age, education, history of hypertension, biomarkers (glycosylated hemoglobin [A1c], body mass index, total cholesterol, triglycerides, serum creatinine, alanine aminotransferase [ALT]), and treatment with renin-angiotensin system inhibitors.

* p<0.05

† p<0.01

‡ p<0.001

Bar graph showing the adjusted odds ratio for albuminuria was higher among those who smoked more in dose-dependent fashion

SOURCE: Reference 442

### Drug Nephrotoxicity

Between 1999 and 2002, 27% of adults in the United States reported habitual use of analgesic and nonsteroidal anti-inflammatory drugs (NSAIDs), including aspirin (470). Cumulative toxicity from prolonged exposure to these drugs is a possible cause of chronic kidney disease, particularly among the elderly and those with diabetes, underlying volume depletion, heart failure, or preexisting kidney dysfunction (471,472,473,474,475). NSAIDs are cyclooxygenase (COX) inhibitors that reduce prostaglandin production in the kidneys and elsewhere. Because kidney perfusion in persons with kidney dysfunction is maintained, in part, by the local synthesis of vasodilating prostaglandins (475,476,477,478), changes in blood flow due to inhibition of prostaglandin synthesis may be responsible for ischemia/reperfusion injury and worsening kidney dysfunction (479,480). Tubulointerstitial changes associated with analgesic use may also influence the progression of a number of kidney diseases (481,482). No data are available comparing the nephrotoxicity profile of various NSAIDs; indomethacin is suggested to cause more hyperkalemia (483) and acute kidney injury (484) than other NSAIDs, and nephritic syndrome is more often associated with fenoprofen (485). Nonetheless, lifetime use of nonnarcotic analgesics among 1,697 women participating in the Nurses’ Health Study was not associated with significant changes in kidney function, even in those who used high doses of these drugs (486). Similarly, among 11,032 initially healthy men in the Physicians’ Health Study (487), moderate analgesic use had an insignificant effect on serum creatinine levels or creatinine clearance over a 14-year period. Subgroup analyses that included those with a history of diabetes or hypertension also found no associations between kidney function decline and consumption of NSAIDs. On the other hand, annual intake of 105–365 acetaminophen pills doubled the odds of ESRD in 242 persons with diabetes, and a cumulative lifetime intake of ≥1,000 tablets nearly tripled the odds (Table 22.20) (475). Interestingly, the introduction of eGFR reporting in the health records of a Scottish population resulted in reduced prescribing of NSAIDs and a significant improvement in eGFR among those who stopped taking NSAIDs, suggesting that eGFR reporting may result in safer prescribing (488).

FIGURE 22.42 Effect of Youth-Onset Type 2 Diabetes on Incidence of End-Stage Renal Disease in Pima Indians, by Diabetes Duration and Age, 1965–2002

Participants were observed from onset of diabetes to outcome or December 2002. Youth-onset type 2 diabetes is defined as onset age <20 years; older-onset type 2 diabetes is defined as onset between ages 20 and 55 years.

Line graphs showing adult-onset compared to youth-onset type 2 diabetes had a cumulative incidence of E S R D that was higher at a comparable duration of diabetes and lower at a comparable age

SOURCE: Left panel: Reference 319, reproduced with permission, copyright © 2006 American Medical Association. All rights reserved. Right panel: Original figure provided by M. E. Pavkov and R. G. Nelson.

TABLE 22.20 Risk of End-Stage Renal Disease in Persons With Diabetes, By Use of Acetaminophen, Aspirin, and Nonsteroidal Anti-Inflammatory Drugs

DRUG | ODDS RATIO OF ESRD (95% CI)^*^
Acetaminophen
Number of pills/year
<105 | Reference
105–365 | 2.1 (1.1–3.8)
≥366 | 1.9 (0.9–3.8)
Number of pills during lifetime
<1,000 | Reference
1,000–4,999 | 2.7 (1.6–4.7)
≥5,000 | 2.6 (1.2–6.0)
Aspirin
Number of pills/year
<105 | Reference
105–365 | 0.9 (0.5–1.5)
≥366 | 0.9 (0.5–1.8)
Number of pills during lifetime
<1,000 | Reference
1,000–4,999 | 0.5 (0.3–0.7)
≥5,000 | 0.7 (0.3–1.4)
Other nonsteroidal anti-inflammatory drugs
Number of pills/year
<105 | Reference
105–365 | 0.9 (0.4–1.8)
≥366 | 0.7 (0.3–1.8)
Number of pills during lifetime
<1,000 | Reference
1,000–4,999 | 0.6 (0.3–1.4)
≥5,000 | 5.8 (0.6–56.2)

Type of diabetes was not specified. CI, confidence interval; ESRD, end-stage renal disease.

* Adjusted for age, sex, race, use of other analgesic drugs, and use of drugs containing phenacetin.

SOURCE: Reference 475

A variety of other commonly used or prescribed medicines have been associated with kidney injuries, including tubulointerstitial and glomerular lesions (489). Two main mechanisms of interaction with kidney structures have been described: direct cellular toxicity and immune-mediated injury. Direct glomerular cell injury was associated with nodular glomerulosclerosis, thrombotic microangiopathy, minimal change disease, and focal segmental glomeruloscrerosis (490). Immune-mediated drug injuries include lupus-like renal lesions, ANCA (anti-neutrophil cytoplasmic antibodies)-related pauci-immune vasculitis, secondary membranous nephropathy, and minimal change disease (Table 22.21) (490). These injuries and the related clinical parameters are generally reversible after withdrawing the offending drug. Nonetheless, establishing a causal link between drug exposure and the development of renal pathology is often difficult, due to lack of specific markers, recall bias, underlying diseases, heterogeneity of symptoms, and physicians’ unfamiliarity with the renal effects caused by certain drugs.

Contrast-induced nephropathy is one of the most commonly reported causes of acute kidney failure in hospitalized patients. Those with diabetes and GFR <60 mL/min/1.73 m^2^ are at particularly increased risk for contrast-induced nephropathy, especially with use of high-osmolar iodinated contrast media (491).

### Autonomic Neuropathy

In the United States, between 25% and 28% of adults age ≥40 years with diabetes have peripheral neuropathy (492). Sympathetic neuropathy with ensuing alteration of glomerular vascular resistance is assumed to hasten deterioration of kidney function in persons with autonomic neuropathy (493). Whether autonomic neuropathy per se is part of the pathogenic process leading to diabetic kidney disease or is a reflection of the severity of diabetes is unclear (493,494,495). Nonetheless, the two complications of diabetes occur together frequently. One study reported that half of the deaths in those with type 1 diabetes and autonomic neuropathy were attributed to diabetic kidney disease (496 More information about diabetic neuropathy is provided in Chapter 23 Peripheral and Autonomic Neuropathy in Diabetes.

TABLE 22.21 Drug-Induced Glomerular Lesions

GLOMERULAR CELL | PATHOLOGY | DRUG
Epithelial cells (podocytes) | Minimal change disease | Interferon α and β, pamidronate, lithium, nonsteroidal anti-inflammatory drugs
Epithelial cells (podocytes) | Focal segmental glomerulosclerosis | Interferon α and γ, pamidronate, lithium, sirolimus, anabolic steroids
Endothelial cells | Thrombotic microangiopathy | Anti-angiogenesis drugs: mitomycin-C, gemcitabine, interferon, cisplatin/carboplatin, estramustine/lomustine, tamoxifen, bleomycin, hydroxyurea, daunorubicin); Antiplatelet agents: ticlopidine, clopidogrel, prasugrel, dipyridamole, defibrotide, interferons, interferon α and β; Immunosuppressive agents: calcineurin inhibitors, anti-CD33 (OKT3); Antimicrobial agents: valacyclovir, penicillins, rifampin, metronidazole, tetracycline, sulfisoxazole, albendazole; Hormones: conjugated estrogens with or without progestins, contraceptives, combination; Nonsteroidal anti-inflammatory drugs: diclofenac, piroxicam, ketorolac; Other: quinine, intravenous oxymorphone (Opana) extended release, simvastatin, iodine, cocaine
Mesangial cells | Idiopathic nodular glomerulosclerosis (mesangial sclerosis) | Heavy tobacco smoking

SOURCE: Reference 490

### Pregnancy

Among women with normal kidney function, regardless of the presence or absence of diabetes, pregnancy is associated with a rise in GFR of about 50% that persists through the 37th week of gestation (274,497) and is accompanied by a moderate increase in urinary protein excretion (274,498). Table 22.22 summarizes ACR and kidney function characteristic of nondiabetic and diabetic pregnancies (499). Most diabetic women with nephropathy have successful pregnancy outcomes. Those with advanced kidney disease, poor glycemic control, or hypertension, however, are at increased risk of pregnancy complications and subsequent deterioration in kidney function (497).

Although neither pregnancy nor parity adversely affect the course of early diabetic kidney disease (500), the few available studies suggest that women with more severe kidney impairment may be at greater risk of progression to ESRD. In a retrospective review of pregnant women with type 1 diabetes, a creatinine clearance <90 mL/min or a urinary protein excretion >1 g/day during the first 20 weeks of gestation was associated with a greater decline in kidney function at approximately 3 years after delivery than in those with less severe nephropathy during early pregnancy (18.9 mL/min/year compared with 6.6 mL/min/year) (501). On average, the creatinine clearance declined from 120±53.1 mL/min (mean±standard deviation) in the first weeks of pregnancy to 77.9±45.4 mL/min at the 3-year follow-up (p=0.01); follow-up proteinuria remained unchanged from the initial measurement during pregnancy (2.94±4.26 g/24 hours vs. 1.74±1.33 g/24 hours, p=0.25) (Table 22.23) (501). Eight of the 34 women who had a follow-up examination maintained a proteinuria level >3 g/24 hours (501). Mothers with advanced kidney disease were more likely to experience preeclampsia and have offspring with low birth weight. Worsening of preexisting diabetic kidney disease was also reported among women with type 1 diabetes who were followed for up to 26 years (502). In this study, morbidity and mortality remained higher in women with pregnancies than in those without 10 years after their last delivery (502). Preeclampsia is more frequent in women with diabetes and is associated with 7.7-fold higher odds of subsequent CKD than in those with normotensive pregnancies (503).

TABLE 22.22 Kidney Function During and After Pregnancy, by Presence or Absence of Diabetes

| DIABETES | | | | GESTATIONAL DIABETES | NO DIABETES
| ACR <30 mg/g Preserved GFR | ACR 30–300 mg/g Preserved GFR | ACR ≥300 mg/g Preserved GFR | Impaired GFR | GESTATIONAL DIABETES | NO DIABETES
Proteinuria | Exaggerated increase | Nephrotic range possible | Nephrotic range typical | | Increases after 20 weeks, normal up to 300 mg/day | Increases after 20 weeks, normal up to 300 mg/day
GFR | Increases | | Variable | | Increases | Increases circa 50%
Preeclampsia | 15%–20% overall in diabetic women, increasing with worsening nephropathy | | | | 7%–10% | 2%–5%
Postpartum proteinuria | None | Usually returns to baseline | | | Increased risk of moderate albuminuria compared with unaffected women | None
Postpartum kidney function | Usually normal | May be equal to prepregnancy decline | | Possible deterioration or accelerated decline | Usually normal | Preeclampsia increases risk of ESRD

ACR, albumin-to-creatinine ratio; ESRD, end-stage renal disease; GFR, glomerular filtration rate.

SOURCE: Reference 499, copyright © 2011 Elsevier, reprinted with permission

TABLE 22.23 Serial Creatinine Clearance and 24-Hour Proteinuria Measurements During and After Pregnancy in Participants With Type 1 Diabetes, 1988–1994

| N | MEAN±STANDARD DEVIATION
| N | Estimated Gestational Age (Weeks) | | | Follow-up^*^
| N | <20 | 20–28 | 28–38 | Follow-up^*^
| | Change in Creatinine Clearance (mL/min)
Initial creatinine clearance
All persons | 45 | 120±53.1 | 112.2±46.1 | 105.3±47.1 | 77.9±45.4
>90 mL/min | 34 | 139±45 | 130±37 | 119±44 | 94±43
60–90 mL/min | 7 | 76±8 | 80±15 | 81±21 | 68±27
<60 mL/min | 4 | 35±12 | 34±6 | 33±18 | 14±8^†^
| | Change in Proteinuria (g/24 h)
Initial collection
All persons | 45 | 1.74±1.33 | 3.60±3.22 | 4.82±4.7 | 2.94±4.26
<1 g/24 h | 20 | 0.68±0.23 | 1.44±1.34 | 2.05±1.51 | 0.82±0.59
1–3 g/24 h | 19 | 2.0±0.59 | 4.81±3.82 | 6.62±5.40 | 2.8±4.11
>3 g/24 h | 6 | 4.44±0.78 | 5.58±1.73 | 8.93±4.52 | 6.71±5.90

* Mean follow-up was 2.8±1.8 years. Follow-up information was obtained for 34 of the 45 women.

† Three persons with kidney transplant

SOURCE: Reference 501, copyright © 1996 Wolters Kluwer Health, reprinted with permission

### Intrauterine Factors

Clinical studies indicate that exposure to a diabetic intrauterine environment increases the risk of kidney disease later in life, perhaps as a consequence of reduced nephron formation during fetal development (504,505,506). Individuals with reduced nephron endowment are also prone to develop hypertension and CVD. These conditions may be triggered or hastened by exposure to additional kidney insults, such as high-salt diet, obesity, and diabetes (504,505,507). Moreover, impaired nephrogenesis and hypertension may be passed to the next generation through changes in epigenetic gene regulation (508,509,510). Consistent quantitative information about this risk comes from longitudinal studies in Pima Indians. Exposure to diabetes in utero among Pima Indians increased nearly fourfold over a 30-year period, paralleled by a doubling in the prevalence of children with diabetes attributable to this exposure (511). Intrauterine exposure to diabetes was associated with a fourfold increase in the age-sex-adjusted incidence of ESRD in young adults with type 2 diabetes, mediated largely by the younger age at onset of diabetes (Figure 22.43) (320). A study exploring the impact of intrauterine exposure to diabetes compared renal vascular resistance in 19 adult nondiabetic offspring of type 1 diabetic mothers with 18 offspring of type 1 diabetic fathers as control subjects (512). At baseline, exposed and control subjects had similar age (median 24 and 25 years, respectively), BMI, age at delivery, glucose concentrations, blood pressure, kidney size, and ^51^Cr-EDTA-measured GFR. Kidney vasodilatation induced with amino acid infusion was associated with significantly less increase in GFR and effective renal plasma flow and less decline in mean arterial pressure in offspring of type 1 diabetic mothers, suggesting a reduced kidney functional reserve possibly due to low nephron number and compensatory permanent single nephron hyperfiltration. A proposed explanation for these observations is that exposure to a diabetic intrauterine environment causes differential apoptosis during nephrogenesis via increased intrarenal renin-angiotensin system activation and nuclear factor (NF)-kappaB signaling (513,514).

A critical shortage of maternal fuels during pregnancy may manifest as intrauterine growth retardation, defined as birth weight below the 10th percentile for gestational age. Low birth weight is frequent in minority populations, in populations undergoing rapid transition from traditional to modern lifestyle, and in those with low socioeconomic status, as well as in pregnancies associated with inadequate maternal weight gain, poor antenatal care, maternal hypertension, or smoking (515). In 12,364 adults with a history of diabetes or hypertension screened by NKF’s KEEP, 15% of whom reported birth weight <2,500 g, a U-shaped relationship was found between birth weight and CKD among men (516). The adjusted odds of developing CKD later in life was 1.6-fold higher among those with a birth weight <2,500 g and 1.4-fold higher among those with a birth weight >4,500 g compared with men of normal birth weight. No association between birth weight and kidney disease was found in women or in African American men included in this study. Similarly, in a population-based, case-control study using 1987–2008 birth certificates from Washington state, low birth weight (400–2,499 g) was associated with twofold higher risk of CKD in the offspring (OR 2.41, 95% CI 2.08–2.80) compared with normal birth weight (2,500–3,999 g); the higher odds persisted after adjustment for maternal diabetes, BMI, and smoking (OR 2.88, 95% CI 2.28–3.63) (517). High birth weight (≥4,000 g) was also positively associated with CKD risk in the unadjusted analysis (OR 1.17, 95% CI 1.03–1.34) but not after adjustment for maternal BMI and smoking (OR 0.97, 95% CI 0.79–1.21). The same study found that children with CKD were more likely to be born to overweight or obese mothers (OR 1.25, 95% CI 1.10–1.41), regardless of maternal diabetes, gestational hypertension, and smoking (Figure 22.44) (517).

### Familial and Genetic Factors

Familial aggregation of diabetic kidney disease and racial/ethnic differences in disease susceptibility suggest a genetic predisposition to diabetic kidney disease. Three initial studies reported familial clustering of diabetic kidney disease (518,519,520). In one study, nephropathy was reported in 83% of the diabetic siblings of persons with type 1 diabetes and kidney disease, but in only 17% of the diabetic siblings of persons with type 1 diabetes without kidney disease (Figure 22.45) (518). Moreover, 41% of the affected siblings of persons with kidney disease had ESRD. A similar study in persons with type 1 diabetes found kidney disease in 33% of the diabetic siblings of diabetic persons with kidney disease but in only 10% of the diabetic siblings of persons without kidney disease (519). Familial clustering is also found in type 2 diabetes. In two generations of Pima Indians with type 2 diabetes (520), the frequency of proteinuria in the diabetic offspring was higher if both diabetic parents had proteinuria than if neither did, and if one parent had proteinuria, the prevalence was intermediate (Figure 22.46).

FIGURE 22.43 Cumulative Incidence of Diabetic End-Stage Renal Disease Among Pima Indians, by Offspring’s Age and Duration of Diabetes, According to Exposure to Diabetes in Utero, 1965–2006

Line graph showing intrauterine exposure to diabetes was associated with a 4-fold increase in incidence of E S R D due to younger age of diabetes onset

SOURCE: Reference 320, copyright © 2010 American Diabetes Association, reprinted with permission from The American Diabetes Association

A number of candidate genes have been identified that may be related to diabetic kidney disease. In Pima Indians, a potential susceptibility locus for ESRD was found within the plasmocytoma variant 1 (PVT1) gene (521), which was confirmed in subjects of European descent with type 1 diabetes (522). Genome-wide association studies of subjects with type 1 diabetes in the Genetics of Kidneys in Diabetes (GoKinD) study (523) found single nucleotide polymorphisms (SNPs) in the FERM domain-containing protein 3 (FRMD3) gene and near the cysteinyl-tRNA synthetase (CARS) gene associated with diabetic kidney disease, defined by overt proteinuria or ESRD. These associations were confirmed in the DCCT/Epidemiology of Diabetes Interventions and Complications (EDIC) prospective study of type 1 diabetes (524), and susceptibility loci near CARS were common to both types of diabetes (525). Engulfment and cell motility 1 (ELMO1) loci were associated with diabetic kidney disease in European (526) and Japanese (527) individuals with type 1 diabetes and in African Americans with ESRD due to type 2 diabetes (528). The Family Investigation of Nephropathy and Diabetes (FIND) study (529) collected DNA and cell lines from European American, African American, American Indian, and Hispanic American families in whom type 2 diabetes was the predominant cause of kidney disease. For all ethnicities combined, the strongest evidence for linkage to diabetic kidney disease was on the long arm of chromosomes 7, 14, 18, and on the short arm of chromosome 10; to ACR on the long arm of chromosomes 2, 7, and 15; and to eGFR on the long arm of chromosomes 1, 7, and 8 (530,531).

FIGURE 22.44 Association Between Birth Weight and Chronic Kidney Disease

The horizontal dashed line represents the reference birth weight (2,500–3,999 g). Birth weight is based on Washington state birth records from 1987–2008. Chronic kidney disease definition is based on International Classification of Diseases, Ninth Revision, diagnosis and procedure codes (753.0, 753.15, 599.6, 753.2). BMI, body mass index.

* Low birth weight (400–2,499 g) data are adjusted for maternal diabetes, BMI, and smoking; high birth weight (≥4,000 g) data are adjusted for maternal BMI and smoking.

Bar graph showing low birth weight children were more likely to have C K D than normal birth weight children after adjustment, while high birth weight was not associated after adjustment

SOURCE: Reference 517

FIGURE 22.45 Kidney Status of Siblings of Type 1 Diabetes Probands, by Diabetic Nephropathy

Probands with diabetic nephropathy were persons with kidney transplant for diabetic ESRD; probands without diabetic nephropathy were persons with albumin excretion rate <45 mg/24 hours. The siblings of probands who were free of diabetic nephropathy (n=12) had less evidence of kidney disease than did siblings of probands who had diabetic nephropathy (n=29) (p<0.001). Numbers on top of the bars are percentages. ESRD, end-stage renal disease.

* Albumin excretion rate ≥45 mg/24 hours.

Bar graph showing 17% of those with a sibling without nephropathy had kidney disease while 83% of those with a sibling with nephropathy had kidney disease

SOURCE: Reference 518

A meta-analysis assessing the effects of all genetic variants associated with severe albuminuria or ESRD found 24 reproducible genetic variants associated with diabetic kidney disease (Figure 22.47) (532). These genetic variants are involved in the renin-angiotensin system, polyol pathway, oxidative stress, inflammation, angiogenesis, glomerular filtration barrier defects, cell growth, differentiation, and apoptosis, supporting their roles in the pathogenesis of diabetic kidney disease (532). Albuminuria and, to a greater degree, GFR are heritable (533), but the actual genes responsible for diabetic kidney disease remain elusive. Although these findings are not universal, they do suggest that genetic factors may predispose some individuals to a higher risk of diabetic kidney disease than others.

FIGURE 22.46 Prevalence of Proteinuria in Offspring, by Number of Parents With Proteinuria, Pima Indians

Proteinuria is defined as urinary protein excretion ≥1 g protein/24 hours. Data are adjusted for age, systolic blood pressure, diabetes duration, and glucose concentration. Prevention of proteinuria in offspring was significantly higher if both parents had proteinuria than if neither parent did; prevalence was intermediate if one parent had proteinuria. Numbers on top of the bars are percentages.

Bar graph showing proteinuria in 46% of those with both parents having proteinuria, 23% in those with 1 parent with it, and 14% in those with neither parent

SOURCE: Reference 520

FIGURE 22.47 Genetic Variants Reproducibly Associated With Diabetic Nephropathy

(A) All genetic variants in or near a gene that were reproduced in an independent study and significantly associated with diabetic nephropathy after meta-analysis. (B) All genetic variants in or near a gene that were reproduced in an independent study and significantly associated with diabetic nephropathy in a subgroup. CI, confidence interval. Parentheses (y-axis labelling) contain the allele used in the comparison. The subgroup in which the genetic variant was reproducibly associated with diabetic nephropathy is shown in y-axis label of Panel B as follows: Asian, T2D (type 2 diabetes), ESRD (end-stage renal disease), T1D (type 1 diabetes), Eur (European), Prot. (proteinuria).

Forest plot showing 24 genetic variants associated with albuminuria or E S R D

SOURCE: Reference 532, copyright © 2011 Springer, reprinted with permission

In addition to specific genetic factors, the multifaceted cross-talk between genes and environmental factors can induce tissue-specific epigenetic changes, i.e., heritable changes in gene expression without alterations in the DNA sequence that can lead to aberrant gene regulation expressed as pathologic phenotype. Epigenetic changes include DNA cytosine methylation, histone posttranslational modifications in chromatin, and noncoding RNAs, all of which can modulate diabetes complications through alterations in gene expression (534). Through epigenetic mechanisms, for example, cells acquire metabolic memory of prior hyperglycemic exposure that appears to mediate the development and progression of diabetic kidney disease (535,536). Hyperglycemia-induced epigenetic aberrations alter transcription factors involved in the expression of genes mediating the pathogenesis of diabetic kidney disease (Figure 22.48) (534). Several microRNAs and certain long noncoding RNAs also have regulatory roles in diabetic kidney disease, including promoting/modulating fibrotic gene expression in renal cells by targeting transcription repressors (535). Although the mechanisms of such cellular memory are not entirely elucidated, its presence is supported by the regression of morphologic lesions in diabetic kidneys after a long period of normoglycemia following pancreas transplantation (361). Similarly, the longlasting effects of previous strict glycemic control observed in persons with type 1 diabetes in the DCCT or type 2 diabetes in the UKPDS could be attributed to cellular metabolic memory. Therapeutic approaches targeting TGF-β, angiotensin II type 1 receptor, or microRNAs can block some of the events involved in the pathogenesis of diabetic kidney disease, suggesting the need for novel therapies.

FIGURE 22.48 Signaling and Epigenetic Networks Involved in the Pathogenesis of Diabetic Complications and Metabolic Memory

Metabolic and hemodynamic disorders associated with diabetes can upregulate growth factors and lipids that trigger signaling pathways, transcription factors, and crosstalk with epigenetic networks. These events can induce chromatin remodeling and changes in the transcriptional regulation of key genes in cells from target tissues. Persistence of epigenetic changes (including histone PTMs, DNAme, and ncRNAs) may lead to metabolic memory, which is known to increase the risk for diabetic complications even after normalization of hyperglycemia. AGE, advanced glycation endproducts; Ang II, angiotensin II; AT1R, angiotensin II type 1 receptor; CD, cluster of differentiation; DNAme, DNA methylation; ECM, extracellular matrix; 1ncRNA, long noncoding RNA; MI, myocardial infarction; miRNA, microRNA; NEFA, nonesterified fatty acids; NF-ĸB, nuclear factor-kappaB; oxLDL, oxidized low-density lipoprotein; PTM, posttranslational modification; RAGE, receptor for AGEs; SR, scavenger; TBR, TGF-β receptor; TGF-β, transforming growth factor beta; Zeb1, zinc finger E-box-binding homebox 1.

Flow chart showing hyperglycemia-induced epigenetic aberrations alter transcription factors involved in the expression of genes mediating the pathogenesis of diabetic kidney disease

SOURCE: Reference 534, copyright © 2015 Springer, reprinted with permission

## Treatment of Diabetic Kidney Disease

A number of large, well-designed clinical trials have examined the effects of treatments on the onset and progression of kidney disease in persons with diabetes. The results of these trials helped inform and refine clinical practice guidelines for the management of persons with diabetes and kidney disease. This section summarizes the current understanding of renoprotective treatments in those with diabetes.

### Metabolic Control

Epidemiologic studies indicate that hyperglycemia plays a fundamental role in the development of diabetic kidney disease, as reviewed previously in this chapter. A number of clinical trials examined the effect of metabolic control on the course of diabetic kidney disease (244,524,537,538,539,540,541,542,543,544,545,546,547,548,549,550,551,552).

In type 1 diabetes, evidence that intensive treatment of hyperglycemia prevents elevation of albuminuria or delays its progression comes from the combined DCCT and its long-term follow-up, the EDIC observational study (524,542). In the DCCT, 1,441 persons with type 1 diabetes were randomly divided into two groups, half receiving intensive insulin therapy and the other half receiving conventional therapy. Participants were followed for a mean of 6.5 years (245). Intensive insulin therapy reduced the risks of moderate albuminuria (≥40 mg/24 hours) and severe albuminuria (≥300 mg/24 hours) by 39% and 54%, respectively. Figure 22.49 shows the cumulative incidence of moderate and severe albuminuria among persons in the DCCT. At the end of the randomization period, the two treatment groups were followed for 8 more years, on average, during the EDIC study to determine the long-term effects of intensive treatment on kidney disease (524). Despite the fact that the difference in A1c levels achieved during the DCCT (7.4% [57 mmol/mol] in the intensive treatment vs. 9.1% [76 mmol/mol] in the conventional treatment group, p<0.01) disappeared promptly during the EDIC study, the beneficial effect of early intensive treatment persisted for 8 years after the end of randomization, with 57% lower adjusted risk for moderate albuminuria and 84% lower risk for severe albuminuria in the former intensively treated group relative to the conventionally treated group (Figure 22.50) (524). In later analyses, although the risk of ESRD did not differ significantly between treatment groups during 22 years of combined follow-up (0.5 cases/1,000 person-years in the intensive treatment and 1.1 cases/1,000 person-years in the conventional treatment group, p=0.10) (542), intensive early metabolic control reduced the risk of impaired GFR, defined as a sustained eGFR <60 mL/min/1.73 m^2^, by 50% (95% CI 18%–69%, p=0.0006). Intensive metabolic control also reduced CVD outcomes by 42%, with a specific 57% decrease in myocardial infarction, stroke, or death from CVD—effects that were partly mediated by the reduced incidence of diabetic kidney disease (543).

The long-term positive effect of intensive glycemic control—the “glycemic legacy”—observed in persons with type 1 diabetes followed in the DCCT/EDIC study (543) was confirmed in those with type 2 diabetes in the UKPDS who were followed for up to 10 years after randomization to an intensively treated or standard care group (544), suggesting that glycemic control is more likely to reduce long-term microvascular and macrovascular complications when introduced early (545,546). The level of glycemic control achieved in the UKPDS was similar to that achieved in the DCCT. Among persons with type 2 diabetes, a meta-analysis of randomized controlled trials (547) exploring the effect of even more intensive glycemic control on microvascular and macrovascular outcomes indicated that more intensive glucose lowering was associated with a significant reduction in the rate of moderate albuminuria only (risk ratio 0.90, 95% CI 0.85–0.96) but had no effects on mortality, kidney failure, or other vascular outcomes. Baseline characteristics and mean A1c levels achieved during standard and intensive glycemic therapy in these clinical trials are shown in Table 22.24 (547,548,549,550,551,552,553). The modest gains in intermediate outcomes across these studies were counterbalanced by a twofold to threefold higher risk of severe hypoglycemia that required the intervention of another person in the intensive treatment arms of the Action to Control Cardiovascular Risk in Diabetes (ACCORD), ADVANCE, and Veterans Affairs Diabetes Trial (VADT) trials (Table 22.25) (551,552,553). The ACCORD trial, targeting an A1c level <6.0% (<42 mmol/mol) in the intensive intervention arm, reported an increased risk of cardiovascular death for intensive versus conventional glycemic control, although it remains unclear whether this effect was related to more hypoglycemic episodes, the use of additional hypoglycemic medicines, or to the target glycemic level itself. Significant weight gain in those receiving intensive treatment might also have offset the beneficial effects of the lower A1c levels. Together, these trials indicate that glycemic control is extremely useful up to a point, but more aggressive glycemic control may be harmful (554).

FIGURE 22.49 Cumulative Incidence of Moderately Elevated Albuminuria and Severe Albuminuria in Participants With Type 1 Diabetes, Diabetes Control and Complications Trial

Moderate albuminuria is defined as an albumin excretion rate ≥40 mg/24 hours; severe albuminuria is defined as albumin excretion rate ≥300 mg/24 hours. In the primary prevention cohort, intensive therapy reduced the adjusted rate of moderate albuminuria by 34% (p=0.04) but did not change the risk of severe albuminuria (p=0.4). In the secondary prevention cohort, intensive treatment reduced the risk of moderate albuminuria by 43% (p=0.001) and the risk of severe albuminuria by 56% (p=0.01).

Line graph showing a higher albuminuria prevalence in those formerly conventionally treated compared to those intensively treated in both the primary and secondary prevention cohort

SOURCE: Reference 245, copyright © 1993 Massachusetts Medical Society, reprinted with permission

Persons with advanced kidney disease experience reduced gluconeogenesis and impaired kidney clearance of insulin and certain oral hypoglycemic drugs (555), potentially increasing the likelihood of severe hypoglycemia, particularly when associated with inadequate food intake. Furthermore, because A1c may underestimate the level of glycemia in uremic patients, due to the shortened lifespan of red blood cells and treatment with erythropoietin, establishing an optimal target A1c in uremic patients remains challenging (556,557). Persons with GFR <60 mL/min/1.73 m^2^ or on dialysis often have higher glycemic levels than expected for a given A1c, albeit with a wide variation in the glucose/A1c relationship (558,559,560,561,562,563). The Dialysis Outcomes and Practice Patterns Study (DOPPS) (564) found a U-shaped association between A1c and all-cause mortality in hemodialysis patients with type 1 or type 2 diabetes. The lowest death rates were associated with A1c levels 7%–7.9% (53–63 mmol/mol), comparable to those found in a population-based study of patients with diabetes and GFR <60 mL/min/1.73 m^2^ who were not on dialysis (565). Another study using time-dependent modeling of A1c values in patients with diabetes on dialysis found similar nonlinear associations with mortality (566). Nevertheless, A1c remains the best clinical marker of long-term glycemic control in persons with diabetes and CKD, particularly if combined with self-monitoring of blood glucose (554). Alternatives to A1c, including measurement of glycated albumin and fructosamine, may be of greater value in these persons, but their clinical value is still being explored.

FIGURE 22.50 Differences in Glycosylated Hemoglobin (A1c) Level and Prevalence and Incidence of Moderate and Severe Albuminuria, by Randomized Treatment Group at the End of the Diabetes Complications and Control Trial and Each Year in the Epidemiology of Diabetes Interventions and Complications Study

(Panel A) Boxes indicate 25th and 75th percentiles of A1c level; whiskers, 5th and 95th percentiles; heavy horizontal lines, medians; thin horizontal lines, means. P values indicate significance of the A1c level between intensive and conventional treatment groups.

(Panel B) Moderate albuminuria is defined as albumin excretion rate ≥28 µg/min, equivalent to 40 mg/24 hours. (A) Prevalence at the end of the DCCT and during the EDIC study. The differences between the treatment groups are significant at each time point after DCCT closeout (p<0.001). (B) Cumulative incidence of new-onset moderate albuminuria during the EDIC study, by treatment group during the DCCT. The cumulative incidence is significantly lower in the former intensive treatment group 8 years after the end of randomization (log-rank test p<0.001).

(Panel C) Severe albuminuria is defined as albumin excretion rate ≥208 µg/min, equivalent to 300 mg/24 hours. (A) Prevalence of severe albuminuria at the end of the DCCT and during the EDIC study. The differences between the treatment groups are significant at each time point after DCCT close-out (p<0.01). (B) Cumulative incidence of severe albuminuria in the EDIC study by former treatment groups. The difference in cumulative incidences is significant by the log-rank test (p<0.001).

Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; DCCT, Diabetes Control and Complications Trial; EDIC, Epidemiology of Diabetes Interventions and Complications study.

Graphs showing 57% lower adjusted risk for moderate albuminuria and 84% lower risk for severe albuminuria in the formerly intensively treated relative to those conventionally treated

SOURCE: Reference 524, reproduced with permission, copyright © 2003 American Medical Association. All rights reserved.

### Blood Pressure Control

Blood pressure control, particularly with RAAS inhibitors, significantly decreases the risk of progression from moderate albuminuria to severe albuminuria, increases the rate of regression from moderate albuminuria to normoalbuminuria, and decreases the risk of heart failure and overall cardiovascular outcomes in persons with diabetic kidney disease, regardless of type of diabetes (567,568,569). Although several types of antihypertensive drugs are effective in ameliorating the progression of diabetic kidney disease, including beta blockers, non-dihydropyridine calcium channel blockers, diuretics, and RAAS inhibitors, the purported relationship between increased intraglomerular pressure and proteinuria that is mediated by RAAS components, as well as their association with virtually every aspect of kidney disease progression, has prompted many investigators to examine the effect of RAAS inhibitors, including primarily ACE inhibitors and ARB, on the progression of diabetic kidney disease.

TABLE 22.24 Characteristics of Persons With Type 2 Diabetes Included in Randomized Controlled Studies of Intensive Versus Conventional Glycemic Treatment

CHARACTERISTICS | STUDY, YEARS OF DATA COLLECTION
CHARACTERISTICS | Kumamoto, NR (Ref. 548) | UKPDS, 1977–1991 (Refs. 549,550) | ACCORD, 2001–2007 (Ref. 551) | ADVANCE, 2001–2007 (Ref. 552) | VADT, 2000–2008 (Ref. 553)
No. of participants | 110 | 4,209 | 10,251 | 11,140 | 1,791
Intensive therapy | 55 | 3,071 | 5,128 | 5,571 | 892
Conventional therapy | 55 | 1,138 | 5,123 | 5,569 | 899
Men (%) | 50 | 47 | 62 | 58 | 97
Age (years) | 49 | 53 | 62 | 66 | 60
Body mass index (kg/m^2^) | 20 | 28 | 32 | 31 | 31
Duration of diabetes (years) | 6.5 | <1 | 10 | 8 | 11.5
Follow-up (years) | 6 | 10 | 3.5 | 5 | 5.6
Previous CVD (%) | 0 | 0 | 35 | 32 | 40
Initial A1c (%) | 9 | 7.1 | 8.3 | 7.5 | 9.4
Final A1c (%)
Intensive group | 7.1 | 7.0 | 6.4 | 6.8 | 6.9
Conventional group | 9.4 | 7.9 | 7.5 | 7.3 | 8.4

Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; ACCORD, Action to Control Cardiovascular Risk in Diabetes; ADVANCE, Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation; CVD, cardiovascular disease; NR, not reported; UKPDS, United Kingdom Prospective Diabetes Study; VADT, Veterans Affairs Diabetes Trial.

SOURCE: Reference 547, copyright © 2011 BMJ Publishing Group, reprinted with permission

TABLE 22.25 Effect of Intensive Versus Conventional Glycemic Control on Kidney Outcomes in Type 2 Diabetes

STUDY, YEARS OF DATA COLLECTION (REF.) | RANDOMIZED INTENSIVE VERSUS CONVENTIONAL GLYCEMIC CONTROL
STUDY, YEARS OF DATA COLLECTION (REF.) | ↓ in New ACR ≥30 mg/g | ↓ in New ACR >300 mg/g | Hazard Ratio (95% CI) | | Risk Ratio (99% CI)
STUDY, YEARS OF DATA COLLECTION (REF.) | ↓ in New ACR ≥30 mg/g | ↓ in New ACR >300 mg/g | Serum Creatinine Doubling | ESRD | ESRD or Serum Creatinine Doubling | Severe Hypoglycemia
Kumamoto, NR (548) | 62% | 100% | NR | NR | NR | NR
UKPDS, 1977–1991 (549,550) | 17% | 34% | p=0.02 | NR | 0.74 (0.26–2.11) | 1.89 (0.69–5.19)
ACCORD, 2001–2007 (551) | 21% | 31% | 1.07 (1.01–1.13) | 0.95 (0.73–1.24) | 1.03 (0.98–1.08) | 3.00 (2.42–3.73)
ADVANCE, 2001–2007 (552) | 8% | 30% | 1.15 (0.82–1.63) | 0.64 (0.38–1.08) | 1.10 (0.70–1.73) | 1.85 (1.30–2.63)
VADT, 2000–2008 (553) | 32% | 37% | p=0.99 | p=0.35 | 1.0 (0.68–1.49) | 2.74 (1.57–4.77)

ACCORD, Action to Control Cardiovascular Risk in Diabetes; ACR, albumin-to-creatinine ratio; ADVANCE, Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation; CI, confidence interval; ESRD, end-stage renal disease; NR, not reported; UKPDS, United Kingdom Prospective Diabetes Study; VADT, Veterans Affairs Diabetes Trial.

SOURCE: References are listed within the table.

A landmark study of 409 mostly hypertensive persons with type 1 diabetes and urinary protein excretion ≥500 mg/24 hours, who were randomized to receive either captopril (an ACE inhibitor) or placebo, found a 48% lower risk of doubling of serum creatinine concentration in the captopril group than in the placebo group after a median follow-up of 3 years (570). The risk of the combined endpoints of death, dialysis, and transplantation was 50% lower (Figure 22.51). A significant renoprotective effect of captopril, however, was limited to those with baseline serum creatinine concentrations ≥1.5 mg/dL. No long-term studies have examined the renoprotective efficacy of ARBs in type 1 diabetes and advanced kidney disease. In persons with type 1 diabetes and lesser levels of ACR, with or without hypertension, randomized controlled studies demonstrate that RAAS inhibitors do not prevent increases in ACR, serum creatinine, or ESRD during up to 5 years of follow-up (Table 22.26) (552,570,571,572,573,574,575,576,577,578,579,580,581,582,583,584,585,586,587). Moreover, when given to normoalbuminuric, normotensive persons with type 1 diabetes, these treatments do not reduce the rate of expansion of the mesangium over a period of 4–5 years (571).

In hypertensive persons with type 2 diabetes and severe albuminuria, the RENAAL study (580) and the Irbesartan Diabetic Nephropathy Trial (IDNT) (581) reported results that were similar to those in persons with type 1 diabetes and severe albuminuria (Table 22.26) (570). The RENAAL study reported a 25% lower risk of doubling of serum creatinine and a 28% decrease in ESRD compared with placebo; the IDNT found a 33% lower risk of doubling of serum creatinine compared with placebo and a 37% lower risk compared with amlodipine. The Irbesartan in Patients With Type 2 Diabetes and Microalbuminuria (IRMA 2) study found that high-dose irbesartan prevented new severe albuminuria in hypertensive persons with moderate ACR levels (579). Although none of these three ARB trials found significant reductions in ESRD incidence during the intervention periods, several cost-benefit analyses based on the IDNT and the cost of medicine and ESRD treatment specific to the United States, Canada, and several European countries, consistently predicted both long-term survival advantage and higher cost-effectiveness with ARB than with other treatments (588). These benefits might be due in part to less comorbidity associated with RAAS treatment, such as heart failure and retinopathy, and in part to lower ESRD incidence when longer time periods are considered. No long-term studies have examined the renoprotective efficacy of ACE inhibitors in persons with type 2 diabetes and ACR ≥300 mg/g. Dual RAAS blockade is at least as effective as monotherapy in reducing blood pressure and albuminuria in persons with diabetes (584,589,590) but is less well tolerated by persons without hypertension or diabetes (582). The Ongoing Telmisartan Alone and in Combination With Ramipril Global Endpoint Trial (ONTARGET) (587) and Veterans Affairs Nephropathy in Diabetes (VA NEPHRON-D) (591) trials found an excess risk of acute kidney injury and hyperkalemia with dual RAAS therapy, without a significant cardiovascular and renal benefit. Further, even after 5 years of treatment, albuminuria increased to pretreatment levels soon after the withdrawal of these drugs (571,572,573). This observation suggests the need for longer periods of normalization of both ACR and glycemic levels to achieve a durable treatment effect on underlying disease processes or more sensitive early markers of kidney disease progression.

FIGURE 22.51 Effect of Captopril on Incidence of Kidney Disease in Persons With Type 1 Diabetes and Proteinuria, 1987–1992

The Collaborative Study included 409 subjects with type 1 diabetes and urinary protein excretion ≥500 mg/24 hours, who were randomized to receive either captopril or placebo and were followed for a median of 3 years. Treatment with captopril was associated with a significant reduction of both endpoints.

Line graph showing captopril resulted in approximately half the risk of doubling serum creatinine and half the risk of death or E S R D after 4 years of follow-up

SOURCE: Reference 570, copyright © 1993 Massachusetts Medical Society, reprinted with permission

TABLE 22.26 Randomized Controlled Studies of Renin-Angiotensin System Inhibitors

STUDY, YEARS OF DATA COLLECTION (REF.) | STUDY CHARACTERISTICS | | | | | | RENAL OUTCOMES
STUDY, YEARS OF DATA COLLECTION (REF.) | Treated | Control | Type of Diabetes | HT | Follow-up (Months) | Baseline ACR Category | Risk Ratio (95% CI)
STUDY, YEARS OF DATA COLLECTION (REF.) | Treated | Control | Type of Diabetes | HT | Follow-up (Months) | Baseline ACR Category | New Moderate or Severe ACR | Doubling in SCR | ESRD
ACE versus placebo or other treatment
RASS, NR (571) | 94 | 95 | 1 | No | 60 | Normal | 0.67 (0.20–2.31) | 0 | 1.67 (0.40–7.00)
EUCLID, NR (572) | 265 | 265 | 1 | No | 24 | Mixed | 0.73 (0.49–1.09) | NR | NR
Lewis, 1987–1992 (570,584) | 207 | 202 | 1 | Yes | 36 | Severe | | 0.67 (0.53–0.84)^*^ | 0.80 (0.62–1.04)^*^
HOPE, NR (573,585) | 34 | 47 | 1 | Yes | 72 | Normal to Moderate | 0.71 (0.39–1.29) | 1.34 (0.68–2.65)^†^ | 2.35 (0.46–12.10)^†^
HOPE, NR (573,585) | 1,774 | 1,722 | 2 | Yes | 72 | Normal to Moderate | 0.75 (0.60–0.90) | 1.34 (0.68–2.65)^†^ | 2.35 (0.46–12.10)^†^
BENEDICT, NR (574) | 301 | 300 | 2 | Yes | 36 | Normal | 0.60 (0.34–1.05) | NR | NR
Ravid, 1990–1997 (575) | 97 | 97 | 2 | Yes | 72 | Normal | 0.34 (0.13–0.90) | 0.38 (0.11–1.40)
ADVANCE, 2001–2008 (552,585) | 5,569 | 5,571 | 2 | Yes | 51.6 | Mixed | 0.84 (0.78–0.90) | 0.62 (0.33–1.15) | 0
ARB versus placebo or other treatment
DIRECT 1, 2001–2008 (576) | 1,662 | 1,664 | 1 | No | 56.4 | Normal | 1.07 (0.53–2.14) | NR | NR
RASS, NR (571) | 96 | 95 | 1 | No | 60 | Normal | 2.64 (1.08–6.45) | 0 | 0
TRANSCEND, 2001–2008 (577) | 2,954 | 2,972 | 1, 2 | Yes | 56 | Normal | 0.75 (0.61–0.92) | 0.99 (0.56–1.76) | 0.50 (0.09–2.71)
DIRECT 2, 2001–2008 (576) | 363 | 362 | 2 | No | 56.4 | Normal | HR 0.73 (0.48–1.10) | NR | NR
DIRECT 2, 2001–2008 (576) | 588 | 592 | 2 | Yes | 56.4 | Normal | HR 1.01 (0.74–1.39) | NR | NR
ROADMAP, 2004–2009 (578) | 2,233 | 2,216 | 2 | Yes | 38.4 | Normal | 0.84 (0.70–1.02) | 2.17 (0.89–5.29) | 0
IRMA 2, NR (579,586) | 194 | 201 | 2 | Yes | 24 | Moderate | HR 0.32 (0.15–0.65) | NR | NR
RENAAL, 1996–2001 (580,586) | 751 | 762 | 2 | Yes | 42 | Severe | NR | 0.84 (0.70–1.01) | 0.77 (0.64–0.93)
IDNT, 1996–2000 (581) | 579 | 569 | 2 | Yes | 31.2 | Severe | NR | 0.71 (0.54–0.92) | 0.83 (0.62–1.11)
ACE versus ARB
RASS, NR (571) | 94 | 96 | 1 | No | 60 | Normal | 0.25 (0.09–0.73) | NR | NR
ONTARGET, NR (582,587) | 2,159 | 4,306 | 1, 2 | Yes | 56 | Normal | 1.04 (0.91–1.17)^‡^ | HR 1.06 (0.70–1.60)^*^,^§^
ONTARGET, NR (582,587) | | | | | | Moderate | 1.04 (0.91–1.17)^‡^ | HR 1.16 (0.73–1.83)^*^,^§^
Barnett, NR (583) | 120 | 130 | 2 | Yes | 60 | Moderate | 1.04 (0.71–1.51) | | 0

ACE, angiotensin-converting enzyme; ACR, albumin-to-creatinine ratio; ADVANCE, Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation; ARB, angiotensin receptor blocker; BENEDICT, Bergamo Nephrologic Diabetes Complications Trial; CI, confidence interval; DIRECT, Diabetic Retinopathy Candesartan Trials; ESRD, end-stage renal disease; EUCLID, EURODIAB Controlled Trial of Lisinopril in Insulin-Dependent Diabetes; HOPE, Heart Outcomes Prevention Evaluation; HR, hazard ratio; HT, hypertension; IDNT, Irbesartan Diabetic Nephropathy Trial; IRMA, Irbesartan Microalbuminuria in Patients With Type 2 Diabetes and Microalbuminuria; NR, not reported; ONTARGET, Ongoing Telmisartan Alone and in Combination with Ramipril Global Endpoint Trial; RASS, Renin Angiotensin System Study; RENAAL, Reduction of Endpoints in Non-Insulin Dependent Diabetes With the Angiotensin II Antagonist Losartan; ROADMAP, Randomized Olmesartan and Diabetes Microalbuminuria Prevention; SCR, serum creatinine; TRANSCEND, Telmisartan Randomised Assessment Study in ACE Intolerant Subject With Cardiovascular Disease.

* Dual versus monotherapy with either ACE or ARB

† Outcome represents type 1 and type 2 diabetes subjects combined.

‡ Outcome represents entire study population.

§ Combined endpoint of chronic dialysis or doubling of serum creatinine

SOURCE: References are listed within the table.

Adding the direct renin inhibitor aliskiren to an ARB (losartan) in persons with type 2 diabetes, hypertension, and ACR ≥300 mg/g more effectively reduced mean urinary ACR than losartan alone (20%, 95% CI 9%–30%, p<0.001) (592); the mean eGFR decline during the 24-week study period also tended to be lower in the aliskiren group (2.4 mL/min/1.73 m^2^ in the aliskiren group vs. 3.8 mL/min/1.73 m^2^ in the placebo group, p=0.07). The Aliskiren Trial in Type 2 Diabetes Using Cardiorenal Endpoints (ALTITUDE), a subsequent, larger study in persons with type 2 diabetes, CKD, and high cardiovascular risk was stopped early due to therapeutic futility and increased risk of stroke and other adverse events (593). Neither ALTITUDE nor VA NEPHRON-D were continued long enough to establish efficacy and remained underpowered for their primary CVD and renal outcomes. Based on their other findings, however, dual RAAS blockade is contraindicated due to safety concerns (554).

In a meta-analysis exploring the benefit of intensive (achieved systolic blood pressure ≤135 mmHg) versus standard (achieved systolic blood pressure ≤140 mmHg) blood pressure targets in subjects with type 2 diabetes, the former was associated with significant 17% and 27% reductions in the odds for moderate and severe albuminuria, respectively (594). For persons with severe albuminuria (>3 g/24 hours), a post hoc analysis from the MDRD study indicated better kidney outcomes with a lower blood pressure goal (<130/80 mmHg) (595). Whereas stringent blood pressure targets lowered the risk for stroke and death, the few studies reporting ESRD or doubling of serum creatinine showed no benefits for these outcomes, suggesting the importance of individualizing blood pressure goals in persons with diabetes to account for the presence and severity of CKD, age, and associated cardiovascular risk. Moreover, ACE inhibitors and beta blockers may be less effective in controlling blood pressure and reducing albuminuria in African Americans than in whites (596,597,598), suggesting that different drug combinations may be more effective in slowing progression of kidney disease in African Americans (599,600).

Table 22.27 shows the Eighth Joint National Committee’s (JNC 8) recommendations for management of hypertension in the population with diabetes and CKD in comparison with other guidelines (600,601,602,603,604). The thresholds and goals recommended by the guideline-writing groups differ within a narrow range, with 2014–2015 recommendations endorsing less intensive and more individualized blood pressure targets for diabetes and CKD than in the past. In elderly persons, in particular, antihypertensive treatment should be individualized, taking into consideration such factors as frailty, comorbidities, and albuminuria (Figure 22.52) (600). There is consensus on the initial use of RAAS treatment in persons with albuminuria, but not for those without elevated albuminuria.

### Control of Blood Lipids

Persons with diabetes and CKD typically have an atherogenic lipid profile, characterized by low concentrations of HDL cholesterol, high concentrations of small, dense LDL cholesterol particles and triglycerides (393,605,606,607). Treatment with lipid-lowering medicines, particularly statins, can reduce the high cardiovascular risk in this population. There is no conclusive evidence, however, that such treatment also affects progression of diabetic kidney disease (608,609,610,611). The Study of Heart and Renal Protection (SHARP) (612) is the largest randomized controlled trial in persons with CKD (average eGFR 27 mL/min/1.73 m^2^) to demonstrate that a lipid-lowering strategy with a statin plus ezetimibe significantly reduces major atherosclerotic events, such as coronary death, myocardial infarction, nonhemorrhagic stroke, and arterial revascularization procedures, compared with placebo (HR 0.83, 95% CI 0.74–0.94). The relative effect on these outcomes was similar in persons with or without diabetes, although the study was not adequately powered for subgroup analyses—only 23% of the 9,438 participants had diabetes. The study detected no effect of lipid-lowering treatment on the frequency of doubling of the baseline serum creatinine concentration or progression to ESRD. This and other studies (613,614,615) found no cardiovascular benefit of statin therapy when it was initiated in persons with diabetes after the onset of dialysis. By contrast, lipid-lowering therapy appears highly beneficial in reducing cardiovascular events in diabetic and nondiabetic persons with a functioning kidney transplant (616).

TABLE 22.27 Guideline Comparisons of Blood Pressure Goals and Drug Therapy for Adults With Hypertension

GUIDELINE, YEAR (REF.) | POPULATION | GOAL BP (mmHG) | INITIAL DRUG TREATMENT OPTIONS | LEVEL OF EVIDENCE
Eighth Joint National Committee (JNC 8), 2014 (600) | Diabetes | <140/90 | Nonblack: thiazide-type diuretic, ACE or ARB, or CCB; Black: thiazide-type diuretic or CCB | Expert opinion
Eighth Joint National Committee (JNC 8), 2014 (600) | CKD | <140/90 | ACE or ARB | Expert opinion
American Diabetes Association (ADA), 2015 (601) | Diabetes | <140/90 | ACE or ARB | Strong
American Diabetes Association (ADA), 2015 (601) | Diabetes + young age | <130/80 | ACE or ARB | Moderate for DBP; Weak for SBP
American Diabetes Association (ADA), 2015 (601) | Diabetes + pregnancy | <110–129/65–79 | Methyldopa, labetalol, diltiazem, clonidine, or prazosin | Expert opinion
American Diabetes Association (ADA), 2015 (601) | Diabetes + CKD | <140/90 | ACE or ARB | Not rated
Canadian Hypertension Education Program (CHEP), 2014 (602) | Diabetes | <130/80 | ACE or ARB—with CVD risk; ACE or ARB, thiazide-type diuretic, CCB—without CVD risk | Weak
Canadian Hypertension Education Program (CHEP), 2014 (602) | CKD + albuminuria^*^ | <140/90 | ACE or ARB | Moderate
European Society of Hypertension/European Society of Cardiology (ESH/ESC), 2013 (603) | Diabetes | <140/85 | ACE or ARB | Strong
European Society of Hypertension/European Society of Cardiology (ESH/ESC), 2013 (603) | CKD no albuminuria | <140/90 | No recommendation | Moderate
European Society of Hypertension/European Society of Cardiology (ESH/ESC), 2013 (603) | CKD + albuminuria | <130/90 | ACE or ARB | Moderate
Kidney Disease: Improving Global Outcome (KDIGO), 2012 (604)^†^ | CKD no albuminuria | ≤140/90 | No recommendation | Moderate
Kidney Disease: Improving Global Outcome (KDIGO), 2012 (604)^†^ | CKD + moderate albuminuria | ≤130/80 | ACE or ARB | Very weak
Kidney Disease: Improving Global Outcome (KDIGO), 2012 (604)^†^ | CKD + severe albuminuria | ≤130/80 | ACE or ARB | Weak
Kidney Disease: Improving Global Outcome (KDIGO), 2012 (604)^†^ | Kidney transplant recipients | ≤130/80 | CCB | Not rated

Albuminuria is defined as ACR ≥30 mg/g. ACE, angiotensin-converting enzyme inhibitor; ACR, albumin-to-creatinine ratio; ARB, angiotensin receptor blocker; BP, blood pressure; CCB, calcium channel blocker; CKD, chronic kidney disease; CVD, cardiovascular disease; DBP, diastolic blood pressure; SBP, systolic blood pressure.

* Defined as urinary protein >500 mg/24 hours or ACR >30 mg/mmol in two of three specimens.

† With or without diabetes

SOURCE: References are listed within the table.

FIGURE 22.52 2014 Hypertension Guideline Management Algorithm, Eighth Joint National Committee

ACEI, angiotensin-converting enzyme inhibitor; ARB, angiotensin receptor blocker; CCB, calcium channel blocker; CKD, chronic kidney disease; DBP, diastolic blood pressure; SBP, systolic blood pressure.

* ACEIs and ARBs should not be used in combination.

† If blood pressure fails to be maintained at goal, reenter the algorithm where appropriate based on the current individual therapeutic plan.

Flow chart demonstrating individualized nature of hypertension management guidelines, taking into consideration factors such as frailty, comorbidities, and albuminuria

SOURCE: Reference 600, reproduced with permission, copyright © 2014 American Medical Association. All rights reserved.

Other lipid-changing medicines may be of value in the management of persons with diabetes and CKD. The Veterans Affairs High-density lipoprotein Intervention Trial (VA-HIT) (617) reported in a post hoc analysis that gemfibrozil reduced risk of major cardiovascular events by 42% compared with placebo in persons with GFR <75 mL/min/1.73 m^2^ and diabetes. The Diabetes Atherosclerosis Intervention Study (DAIS) (618) and the Fenofibrate Intervention and Event Lowering in Diabetes (FIELD) study (619,620) both found that fenofibrate significantly lowered the risk of new-onset moderate albuminuria and promoted regression from moderate to normal albuminuria compared with placebo in persons with type 2 diabetes. On the other hand, fenofibrate did not change the risk of progression from moderate to severe albuminuria.

### Dietary Modification

In animals with experimental diabetes, reduced protein intake protects against hyperfiltration and progressive sclerosis of functioning glomeruli (621,622). In persons with type 1 diabetes and normal urinary albumin excretion, short-term dietary protein restriction favorably modifies glomerular hemodynamic function, and in those with moderate albuminuria, it also reduces urinary albumin excretion (623,624,625,626,627). Similar effects were found in persons with clinical proteinuria (Table 22.28) (628,629,630,631). The largest of these studies (632) randomized 82 persons with type 1 diabetes, severe albuminuria, and prerandomization GFR decline of 7.1 mL/min/year to usual-protein diet (1.02 g/kg/day, 95% CI 0.95–1.10) and reduced-protein diet (0.89 g/kg/day, 95% CI 0.83–0.95) (p=0.005) for a period of 4 years. At the end of the study, the CVD-adjusted risk of ESRD or death was 0.23 (95% CI 0.07–0.72, p=0.01) in the group receiving the reduced-protein diet compared with the group receiving the usual diet (Figure 22.53), suggesting that even moderate protein restriction, which moves intakes from excess toward the norm, provides benefits beyond conventional drug therapy in these persons.

TABLE 22.28 Clinical Trials of the Effect of Dietary Protein Reduction on the Course of Diabetic Nephropathy in Persons With Type 1 Diabetes and Severe Albuminuria

LOCATION (REF.) | NO. OF PERSONS | TREATMENT DURATION (MONTHS) | PROTEIN RESTRICTION (G/KG/DAY) | OUTCOME IN TREATMENT GROUP
Italy (628) | 16 | 4.5 | 0.7 | Decreased urinary albumin excretion
Texas (629) | 11 | 24 | 0.6 | Decreased urinary protein excretion
United Kingdom (630) | 19 | 33 | 0.7 | Decreased rate of GFR decline; decreased urinary albumin excretion
Not reported (631) | 35 | 34.7 | 0.6 | Decreased rate of GFR decline; decreased urinary albumin excretion

In the studies in References 628 and 631, a protein-restricted diet was compared with a standard diet; in Reference 629, there was no control group; in Reference 630, subjects were compared before and after dietary protein restriction. Severe albuminuria is defined by proteinuria ≥0.5 g/24 hours. GFR, glomerular filtration rate.

SOURCE: References are listed within the table.

FIGURE 22.53 Cumulative Incidence of End-Stage Renal Disease or Death in Persons With Type 1 Diabetes, by Protein Intake

Eighty-two persons with severe albuminuria were randomized to usual-protein diet and low-protein diet. The numbers at the bottom of the figure represent the number of persons in each group at risk for the event at baseline and after each 6-month period (p=0.042). ESRD, end-stage renal disease.

Line graph showing a reduced protein diet resulted in lower risk of death or E S R D

SOURCE: Reference 632, copyright © 2002 Elsevier, reprinted with permission

Fewer studies are available in persons with type 2 diabetes. A study of the efficacy of dietary protein restriction in 160 persons with type 2 diabetes and moderate albuminuria or ≥5 years duration of diabetes found no beneficial effect of protein restriction on albuminuria or eGFR over a mean follow-up of 28 months (633). In fact, a protein intake restricted to 0.8 g/kg/day could not be effectively achieved beyond the first 6 months of the study, reflecting the inconvenience associated with a strict dietary regimen that may outweigh the benefits of such therapy. A systematic review of randomized studies (634) concluded that a reduced-protein diet in persons with CKD associated with either type of diabetes had no significant effect on kidney function relative to normal protein consumption, despite improvements in proteinuria and A1c, and that dietary protein restriction may significantly increase the risk for malnutrition in those with more advanced CKD (635). On the other hand, studies evaluating a reduction or alteration of protein intake in persons with diabetes and CKD are generally small (under 100 subjects), of short duration (<2 years), have limited documentation on the quality of protein (animal or vegetable), fat and carbohydrate intake, and evaluate intermediate outcomes, i.e., albuminuria and eGFR, rather than major health outcomes.

Sodium intake is a major contributor to blood pressure increase. According to the Institute of Medicine (636), about 75% of dietary sodium intake is obtained from preprocessed foods or is added to restaurant food during preparation, and only about 25% comes from natural sources or is added by the consumer. The Dietary Guidelines for Americans (637) recommends that persons age ≥51 years, African Americans, and persons with hypertension, diabetes, or CKD limit their sodium intake to 1,500 mg daily. In the NHANES 2005–2008, virtually all (99.4%) of those encouraged to limit their sodium intake exceeded the recommended limit on a daily basis (638). Although sodium reduction has a positive impact on blood pressure in persons with diabetes (639), its long-term effect on kidney outcomes remains unclear. Most individuals may benefit from a Dietary Approaches to Stop Hypertension (DASH) diet, a reduced sodium diet emphasizing fruits, vegetables, low-fat dairy foods, whole grains, nuts, poultry, fish, and smaller amounts of red meat and refined sugars than the typical diet in the United States (640). The DASH diet reflects a shift towards whole-diet approaches to the management of CKD in diabetes that integrates multiple healthful eating goals simultaneously, without a focus on single nutrients. In addition to lowering blood pressure, a DASH-type diet reduced kidney function loss over 11 years in women from the Nurses’ Health Study with mildly decreased eGFR, an effect primarily associated with reduced red meat intake (641). Nonetheless, the DASH diet may not be suitable, without modification, for persons with GFR <60 mL/min/1.73 m^2^ because of its high content of potassium (4.5 g/day), phosphorus (1.7 g/day), and protein (1.4 g/kg/day).

### Other Treatments

Modification of blood pressure, metabolic control, diet, and treatment with dialysis or transplantation are the mainstays of treatment of kidney disease in persons with diabetes, and a majority of the research into new therapeutic approaches has focused on one or more of these therapies. Nevertheless, a growing body of evidence indicates that the development of diabetic kidney disease is related to specific metabolic derangements induced by hyperglycemia that interplay with hemodynamic pathways. Advanced glycation endproducts (642), TGF-β, and other growth factors (643,644,645,646) play key roles in promoting chemical, cellular, and tissue disorders linked to progression of kidney disease. Animal studies suggest that inhibitors of advanced glycation endproduct formation ameliorate glomerulosclerosis and improve albuminuria and kidney function (647), and advanced glycation endproduct crosslink breakers improve endothelial function and arterial compliance, with reductions in arterial pulse pressure and albuminuria in persons with type 1 diabetes (648,649). Antioxidant inflammation modulators, such as eicosapentaenoic acid or pentoxifylline (650,651), improved kidney function and proteinuria in small studies of persons with type 1 or type 2 diabetes, and treatment with Rho GTPase and Rho-associated kinase inhibitors (ROCKs) mitigated mesangial expansion, thickening of glomerular basement membrane, and albuminuria in experimental diabetic kidney disease (652).

Persons with diabetes and CKD require multidisciplinary management involving a combination of all treatments and behavioral adjustments to hold off the progression of kidney disease per se and to prevent the associated complications. The Steno-2 study, a landmark prospective, randomized trial in Denmark (653), demonstrated that intensive multifactorial intervention reduces the incidence of microvascular and macrovascular outcomes in patients with type 2 diabetes and persistent moderate albuminuria. At the end of the randomization period (mean duration 7.8 years), participants in the intervention arm (n=80) had significantly lower systolic and diastolic blood pressure, A1c, total cholesterol, LDL cholesterol, triglycerides, and ACR than those randomized to conventional treatment (n=80). Although these differences disappeared during the 5.5 years of post-trial observational follow-up, intensive therapy reduced the risk of death (HR 0.54, 95% CI 0.32–0.89, p=0.02), death from CVD (HR 0.43, 95% CI 0.19–0.94, p=0.04), severe albuminuria (HR 0.44, 95% CI 0.25–0.77, p=0.04), diabetic retinopathy (HR 0.57, 95% CI 0.37–0.88, p=0.01), and autonomic neuropathy (HR 0.53, 95% CI 0.34–0.81, p=0.004) during the entire 13.3-year study period.

## Other Kidney Diseases Associated With Diabetes

### Infections

#### Urinary Tract Infections

Persons with diabetes may be more susceptible to infections of the urinary tract. Autopsy studies from the preantibiotic era (654,655,656,657,658) reported 10%–20% prevalence of histologic pyelonephritis in persons with diabetes, five times that of persons without diabetes. Not only was the frequency of urinary tract infection greater in those with diabetes at that time, but the infections were often more serious and protracted (655). With the introduction of effective antimicrobial therapy, the frequency and severity of urinary tract infections may have diminished (659). Additional information about urinary tract infections in persons with diabetes is provided in Chapter 28 Urologic Diseases and Sexual Dysfunction in Diabetes and Chapter 30 Infections Associated With Diabetes.

Table 22.29 presents the prevalence of asymptomatic bacteriuria in persons with and without diabetes from several different clinic- or hospital-based populations (660,661,662,663,664,665,666,667,668,669,670,671,672,673,674,675,676,677). In a systematic review and meta-analysis of published data since 1966, women with diabetes have about three times the frequency of bacteriuria as nondiabetic women (OR 2.6, 95% CI 1.6–4.1), and men with diabetes have about four times the frequency of bacteriuria as healthy control subjects (OR 3.7, 95% CI 1.3–10.2) (660,665,666,670,678,679,680,681,682,683,684,685). Some studies report a longer duration of diabetes in women with asymptomatic bacteriuria than in those without (pooled difference 0.17 years, 95% CI 0.03–0.31, p=0.01), but the same review found no difference in A1c (660). Some studies show a relationship between asymptomatic bacteriuria in diabetic persons and the more frequent development of genitourinary tract infections (677,686,687,688,689), but others show no relationship (659,690). In most studies, the microorganisms causing asymptomatic bacteriuria in persons with diabetes are similar to those causing bacteriuria in nondiabetic persons (659), but a survey of 514 diabetic and 405 nondiabetic subjects found that nearly half of the diabetic subjects with bacteriuria were infected by bacteria other than E. coli, whereas all but one case of bacteriuria in the nondiabetic subjects were caused by E. coli (679). The prevalence of asymptomatic bacteriuria is not influenced by the type of diabetes (659,660).

TABLE 22.29 Prevalence of Asymptomatic Bacteriuria in Populations With and Without Diabetes

LOCATION, YEARS OF DATA COLLECTION (REF.) | NO. DIABETES/CONTROL | MEAN AGE (YEARS) (DIABETES/CONTROL) | PATIENT SOURCE (DIABETES/CONTROL) | POPULATION | TYPE OF DIABETES | PREVALENCE N (%)
LOCATION, YEARS OF DATA COLLECTION (REF.) | NO. DIABETES/CONTROL | MEAN AGE (YEARS) (DIABETES/CONTROL) | PATIENT SOURCE (DIABETES/CONTROL) | POPULATION | TYPE OF DIABETES | Diabetes | Controls
Israel, 2002–2003 (661) | 411/160 | 59.6/53.3 | Outpatient clinics | Women | 2 | 25 (6) | 4 (3)
Italy, 1997–2000 (662) | 228/146 | 57.7/59.0 | Outpatient clinics | Women | 1, 2 | 40 (18) | 27 (18)
Zimbabwe, 1999–2000 (663) | 123/53 | 51.0/46.0 | Outpatient clinics | Africans | 1, 2 | 39 (32) | 6 (11)
Turkey, 1988–1989 (664) | 110/100 | Not available | Hospital | Men and women | 1, 2 | 6/64 (9) women, 1/46 (2) men | 0/56 (0) women, 0/44 (0) men
California, NR (665) | 752/200 | 55.0/54.0 | Outpatient clinics | Men and women | 2 | 31/341 (9) women, 1/411 (0.2) men | 5/100 (5) women, 0/100 (0) men
Nigeria, NR (666) | 190/190 | Not available | Outpatient clinics | Africans | 1, 2 | 9/100 (9) women, 3/90 (3) men | 8/100 (8) women, 2/90 (2) men
Hungary, NR (667) | 133/178 | 15.6/14.1 | Outpatient clinic/medical students | Youth | 1 | 14/64 (22) women, 8/66 (12) men | 5/84 (6) women, 0/94 (0) men
Chile, NR (668) | 50/50 | Not available | Outpatient clinics | Women | 2 | 16 (32) | 2 (4)
India, NR (669) | 87/93 | 18–60/18–60 (range) | Outpatient clinics | Men and women | 1, 2 | 5/42 (12) women, 2/48 (4) men | 4/48 (8) women, 1/45 (2) men
South Africa, NR (670) | 100/36 | 57.0/72.0 | Outpatient clinics | Men and women | 1, 2 | 8/60 (13) women | 1/36 (3)
Hungary, NR (671) | 178/194 | 15.1/14.4 | Outpatient clinics | Children and adolescents | 1 | 14/67 (21) women, 8/66 (12) men | 5/84 (6) women, 0/94 (0) men
Iran, 2004 (672) | 202 | 56.0 | Outpatient clinics | Women | 2 | 22 (11)
Canada, 1989–1993 (673) | 1,072 | >16 | Outpatient clinics | Women | 1, 2 | 85 (8)
Washington, 1998–2002 (674) | 218/799 | Not available | Epidemiologic cohort study | Postmenopausal women | 1, 2 | 14 (6) | 32 (4)
Greece, 2001–2002 (675) | 363/350 | 61.3/63.0 | Outpatient clinics | Women | 2 | 35 (10) | 10 (3)
Netherlands, 1996–1997 (676,677) | 636/153 | 59.4 | Outpatient clinic/health center | Women | 1, 2 | 163 (26) | 9 (6)

NR, not reported.

SOURCE: Reference 660 and references listed within the table.

The prevalences of cystitis and pyelonephritis in 550 women with type 1 diabetes in the UroEDIC survey—EDIC year 10 subjects surveyed for urologic complications of type 1 diabetes—were 15% and 3% during the preceding 12 months (691). Table 22.30 presents risk factors for urinary tract infections in this cohort. The prevalence of cystitis in UroEDIC women was similar to that in nondiabetic white women age 20–59 years from the NHANES III. Among the men in UroEDIC, the prevalence of urinary tract infections was 4% for cystitis and 0% for pyelonephritis, too low to be included in the risk factor evaluation.

#### HIV

Diabetes and hypertension associated with HIV infection are described as risk factors for the development of HIV-associated immune complex kidney disease (692,693,694). While hypertension may be a consequence of HIV-related kidney disease, the association with diabetes appears to be mediated by post-infectious glomerulonephritis (692,695). A cross-sectional comparison of persons with type 2 diabetes with and without HIV infection and persons with HIV infection only is presented in Table 22.31 (696). Among the 73 HIV-infected persons with type 2 diabetes, the combination of diabetes, higher HIV viral load, and antiretroviral treatment with abacavir was a significant predictor of ACR ≥30 mg/g. Antiretroviral therapy has nephrotoxic effects, including tubulointerstitial nephropathies, proximal tubular dysfunction, Fanconi’s syndrome, and nephrogenic diabetes insipidus (697). Chapter 6 Other Specific Types of Diabetes provides additional information about the relationship of diabetes with HIV infection and drugs for HIV therapy.

TABLE 22.30 Adjusted Odds Ratios for Cystitis and Pyelonephritis in Women With Type 1 Diabetes Participating in the Uro-EDIC Survey, 2002–2004

CHARACTERISTICS | ODDS RATIO (95% CI)
CHARACTERISTICS | Cystitis^*^ | Pyelonephritis^†^
Conventional versus intensive treatment (DCCT) | 0.70 (0.40–1.22) | 0.19 (0.04–0.85)
Primary versus secondary DCCT cohort | 1.60 (0.92–2.79) | 0.71 (0.19–2.76)
Age (per 1-year increase) | 0.98 (0.94–1.03) | 0.95 (0.85–1.07)
After versus before menopause | 1.41 (0.66–3.00) | 1.02 (0.15–6.87)
Composite vascular complication score^‡^
0 | 1 | 1
1 | 2.09 (1.12–3.91) | NR
2–4 | 0.96 (0.26–3.52) | NR
1–4 | NR | 4.48 (1.08–18.54)
Sexual activity last 12 months | 8.28 (1.45–158.32)^§^ | 0.90 (0.10–7.76)

The study included 550 women with type 1 diabetes participating in the Uro-EDIC survey. CI, confidence interval; DCCT, Diabetes Control and Complications Trial; NR, not reported; Uro-EDIC, ancillary study of urologic complications in the DCCT/Epidemiology of Diabetes Interventions and Complications (EDIC) cohort.

* Additional covariates in the cystitis multivariate model were not statistically significant at p≤0.01, including race (p=0.05), frequency of sexual intercourse in the last 12 months (p=0.43), exercise (p=0.20), alcohol use (p=0.13), total cholesterol (p=0.11), or triglycerides (p=0.22).

† Additional covariates in the pyelonephritis multivariate model were not statistically significant at p≤0.01, including smoking (p=0.06), oral contraceptive use (p=0.04), or diabetic ketoacidosis ever (p=0.39).

‡ Composite vascular complication score of 0 to 4 is based on a history of proliferative retinopathy, nephropathy, neuropathy, or cardiovascular/cerebrovascular event.

§ Likelihood ratio test

SOURCE: Reference 691, copyright © 2009 Elsevier, reprinted with permission

### Renal Papillary Necrosis

Impaired blood flow to the inner medulla and papilla of the kidney can lead to anoxic damage and ultimately to renal papillary necrosis. Sloughing of the renal papilla may ensue, which can obstruct the renal pelvis. Individuals may remain asymptomatic or develop flank pain and renal colic. Historically, the prevalence of renal papillary necrosis at autopsy is 20–30 times as great in persons with diabetes as in those without (698). Among persons with diabetes, it occurs bilaterally in half of the cases and is 2.5 times as frequent in women as in men (655,656,699). Moreover, persons with diabetes and acute pyelonephritis are at particularly high risk of renal papillary necrosis. In one study, 27% of diabetic subjects with renal papillary necrosis at autopsy also had acute fulminant pyelonephritis (656). A review of the medical records of the 165 patients diagnosed with renal papillary necrosis at the Mayo Clinic between 1976 and 1992 showed that among patient groups with diabetes, analgesic abuse, or urinary tract infections, the diagnosis was more frequent in women than men (700). The 10-year survival rate from the time of diagnosis was significantly lower for patients with diabetes than without (44% vs. 77%), and progression to ESRD was more frequent in the presence of diabetes.

TABLE 22.31 Demographic and Clinical Characteristics of Subjects With HIV, Diabetes, and Both HIV and Diabetes, 2007–2009

CHARACTERISTICS | HIV+ AND DIABETES | HIV+ | DIABETES | P-VALUE
N | 73 | 82 | 61
Age (years) | 52±1 | 45±1 | 51±1 | <0.0001^*^
Age (years) | 52±1 | 45±1 | 51±1 | 0.9^†^
Age (years) | 52±1 | 45±1 | 51±1 | <0.0001^‡^
Race/ethnicity (%) | | | | 0.0002
Caucasian | 18 | 48 | 25
African American | 74 | 38 | 67
Hispanic | 5 | 7 | 8
Asian | 1 | 6 | 0
Other | 2 | 1 | 0
Sex (%) | | | | 0.1
Male | 63 | 78 | 67
Female | 37 | 22 | 33
BMI (kg/m^2^) | 31±1 | 26±1 | 35±1 | <0.0001^*^
BMI (kg/m^2^) | 31±1 | 26±1 | 35±1 | 0.001^†^
BMI (kg/m^2^) | 31±1 | 26±1 | 35±1 | <0.0001^‡^
Systolic BP (mmHg) | 131±2 | 123±1 | 127±3 | 0.002^*^
Systolic BP (mmHg) | 131±2 | 123±1 | 127±3 | 0.16^†^
Systolic BP (mmHg) | 131±2 | 123±1 | 127±3 | 0.13^‡^
Diastolic BP (mmHg) | 80±1 | 77±1 | 77±1 | 0.18
RAAS use (%) | 49% | 20% | 64% | <0.0001^*^
RAAS use (%) | 49% | 20% | 64% | 0.09^†^
RAAS use (%) | 49% | 20% | 64% | <0.0001^‡^
Duration diabetes (years) | 6.8±0.7 | | 6.2±0.8^§^ | 0.53
Current insulin use (%) | 29 | | 21 | 0.32
A1c | 7.1±0.2 | | 7.8 ±0.3 | 0.03
Duration HIV (years) | 13±1 | 14±1 | | 0.38
CD4 (cells/mL) | 588±32 | 522±30 | | 0.13
HIV VL <50 copies/mL (%) | 56 | 81 | | 0.0007
Current ARV therapy (%) | 77 | 94 | | 0.002
ARV therapy naïve (%) | 15 | 1 | | 0.0006
Duration ARV therapy (years) | 7.7±0.6 | 7.9 ±0.5 | | 0.8
Serum creatinine (mg/dL) | 0.96±0.02 | 0.98±0.02 | 0.94±0.02 | 0.45
GFR (mL/min) | 82.0±2.3 | 88.1±2.2 | 82.6±1.9 | 0.09
ACR (mg/g) | 117.5 ±36.8 | 17.7±5.4 | 59.9±32.2 | <0.0001^*^
ACR (mg/g) | 117.5 ±36.8 | 17.7±5.4 | 59.9±32.2 | 0.1^†^
ACR (mg/g) | 117.5 ±36.8 | 17.7±5.4 | 59.9±32.2 | 0.04^‡^

Data are from a cross-sectional study including 73 HIV-infected adults with type 2 diabetes, 82 HIV-infected adults without diabetes, and 61 control subjects without HIV or diabetes. Conversions for A1c values are provided in Diabetes in America Appendix 1 Conversions. A1c, glycosylated hemoglobin; ACR, urinary albumin-to-creatinine ratio; ARV, antiretroviral therapy; BMI, body mass index; BP, blood pressure; CD4, cluster of differentiation 4; GFR, glomerular filtration rate, calculated using the Cockroft-Gault equation; HIV, human immunodeficiency virus; RAAS, renin-angiotensin aldosterone system; VL, viral load.

* p-value for HIV+ diabetes+ versus HIV+

† p-value for HIV+ diabetes+ versus diabetes+

‡ p-value for HIV+ versus diabetes+

§ Data were available on 43 subjects.

SOURCE: Reference 696

## Conclusions

Chronic kidney disease is a public health problem that affects nearly 14% of the U.S. population and is disproportionately distributed among minority and disadvantaged groups. Most risk factors for CKD are modifiable; therefore, public health strategies targeting these factors may significantly reduce the disease burden.

Diabetes is the leading cause of CKD, and the increasing prevalence of diabetes together with improved availability of dialysis and transplants have sustained a continued rise in the proportion of CKD attributable to diabetes since the 1980s. In persons with type 1 diabetes, the incidence of CKD has declined in parallel with a significant trend for earlier initiation of antihypertensive treatment following the onset of diabetes, expansion of RAAS inhibitor usage, and sustained improvements in glycemic control. On the other hand, in persons with type 2 diabetes, the incidence of CKD does not appear to be declining, possibly due to the higher number and prevalence of CKD risk factors associated with type 2 diabetes that outweigh current treatment options or their effectiveness. An ever-increasing number of persons with diabetes, 91% of whom have type 2 diabetes, are requiring renal replacement therapy, at enormous cost to patients, their families, and to society.

Improved management of hyperglycemia, hypertension, hyperlipidemia, and albuminuria have dramatically slowed progression to ESRD, as illustrated by a level incidence of ESRD attributed to diabetes since 2005. Trends in the incidence of ESRD due to diabetes, however, differ broadly by age and race/ethnicity. At the national level, the incidence of ESRD in persons with a primary diagnosis of diabetes remains higher in African Americans, Mexican Americans, Asians, and American Indians than in whites, with the highest rates being found in African Americans and American Indians.

## List of Abbreviations

A1c: glycosylated hemoglobin
ABCA1: ATP-binding cassette transporter
ACCORD: Action to Control Cardiovascular Risk in Diabetes
ACE: angiotensin-converting enzyme
ACR: albumin-to-creatinine ratio
ADA: American Diabetes Association
ADVANCE: Action in Diabetes and Vascular Disease: Preterax and Diamicron Modified Release Controlled Evaluation
AER: albumin excretion rate
ALTITUDE: Aliskiren Trial in Type 2 Diabetes Using Cardiorenal Endpoints
ARB: angiotensin receptor blocker
ATP: adenosine triphosphate
BMI: body mass index
CI: confidence interval
CKD: chronic kidney disease
CVD: cardiovascular disease
DASH: Dietary Approaches to Stop Hypertension
DCCT: Diabetes Control and Complications Trial
DNA: deoxyribonucleic acid
EDC: Epidemiology of Diabetes Complications study
EDIC: Epidemiology of Diabetes Interventions and Complications study
EDTA: ethylenediaminetetraacetic acid
eGFR: estimated glomerular filtration rate
ESRD: end-stage renal disease
FinnDiane: Finnish Diabetic Nephropathy study
GFR: glomerular filtration rate
HDL: high-density lipoprotein
HIV: human immunodeficiency virus
HR: hazard ratio
IDNT: Irbesartan Diabetic Nephropathy Trial
KDIGO: Kidney Disease: Improving Global Outcomes
KEEP: Kidney Early Evaluation Program
LDL: low-density lipoprotein
MDRD: Modification of Diet in Renal Disease
NHANES: National Health and Nutrition Examination Survey
NKF: National Kidney Foundation
NSAID: nonsteroidal anti-inflammatory drugs
OR: odds ratio
RAAS: renin-angiotensin-aldosterone system
RENAAL: Reduction of Endpoints in Non-insulin dependent diabetes with the Angiotensin II Antagonist Losartan
SMR: standardized mortality ratio
TGF-β: transforming growth factor beta
UKPDS: United Kingdom Prospective Diabetes Study
UroEDIC: ancillary study of urologic complications in the DCCT/EDIC cohort
USRDS: United States Renal Data System
VA NEPHRON-D: Veterans Affairs Nephropathy in Diabetes
VLDL: very low-density lipoprotein

## References

1 United States Renal Data System: USRDS 2014 Annual Data Report: an Overview of the Epidemiology of Kidney Disease in the United States. Bethesda, MD: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, 2014. Disclaimer: The data reported here have been supplied by the United States Renal Data System (USRDS). The interpretation and reporting of these data are the responsibility of the author(s) and in no way should be seen as an official policy or interpretation of the U.S. government.
2 United States Renal Data System: USRDS 2013 Annual Data Report: Atlas of Chronic Kidney Disease and End-Stage Renal Disease in the United States. Bethesda, MD: National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases, 2013. Disclaimer: The data reported here have been supplied by the United States Renal Data System (USRDS). The interpretation and reporting of these data are the responsibility of the author(s) and in no way should be seen as an official policy or interpretation of the U.S. government.
3 Centers for Disease Control and Prevention: Prevalence of chronic kidney disease and associated risk factors—United States, 1999–2004. MMWR Morb Mortal Wkly Rep 56:161–165, 2007 17332726
4 Yokoyama H, Okudaira M, Otani T, Sato A, Miura J, Takaike H, Yamada H, Muto K, Uchigata Y, Ohashi Y, Iwamoto Y: Higher incidence of diabetic nephropathy in type 2 than in type 1 diabetes in early-onset diabetes in Japan. Kidney Int 58:302–311, 2000 10886575
5 Dart AB, Martens PJ, Rigatto C, Brownell MD, Dean HJ, Sellers EA: Earlier onset of complications in youth with type 2 diabetes. Diabetes Care 37:436–443, 2014 24130346
6 TODAY Study Group, Zeitler P, Hirst K, Pyle L, Linder B, Copeland K, Arslanian S, Cuttler L, Nathan DM, Tollefsen S, Wilfley D, Kaufman F: A clinical trial to maintain glycemic control in youth with type 2 diabetes. N Engl J Med 366:2247–2256, 2012 22540912
7 National Kidney Foundation: K/DOQI clinical practice guidelines for chronic kidney disease: evaluation, classification, and stratification. Am J Kidney Dis 39(2 Suppl 1):S1–S266, 2002 11904577
8 Kidney Disease: Improving Global Outcomes (KDIGO) CKD Work Group: KDIGO 2012 clinical practice guideline for the evaluation and management of chronic kidney disease. Kidney Int Suppl 3:1–150, 2013
9 American Diabetes Association: Microvascular complications and foot care. Sec. 10. In “Standards of Medical Care in Diabetes—2017.” Diabetes Care 40(Suppl 1):S88–S89, 2017 27979897
10 Levey AS, Bosch JP, Lewis JB, Greene T, Rogers N, Roth D: A more accurate method to estimate glomerular filtration rate from serum creatinine: a new prediction equation. Modification of Diet in Renal Disease Study Group. Ann Intern Med 130:461–470, 1999 10075613
11 Stevens LA, Coresh J, Feldman HI, Greene T, Lash JP, Nelson RG, Rahman M, Deysher AE, Zhang YL, Schmid CH, Levey AS: Evaluation of the Modification of Diet in Renal Disease Study equation in a large, diverse population. J Am Soc Nephrol 18:2749–2757, 2007 17855641
12 Miller WG: Estimating glomerular filtration rate. Clin Chem Lab Med 47:1017–1019, 2009 19728841
13 Levey AS, Stevens LA, Schmid CH, Zhang YL, Castro AF, 3rd, Feldman HI, Kusek JW, Eggers P, Van Lente F, Greene T, Coresh J; CKD-EPI (Chronic Kidney Disease Epidemiology Collaboration): A new equation to estimate glomerular filtration rate. Ann Intern Med 150:604–612, 2009 19414839
14 National Kidney Foundation: KDOQI clinical practice guidelines and clinical practice recommendations for diabetes and chronic kidney disease. Am J Kidney Dis 49(Suppl 2):S1–S180, 2007
15 He F, Xia X, Wu XF, Yu XQ, Huang FX: Diabetic retinopathy in predicting diabetic nephropathy in patients with type 2 diabetes and renal disease: a meta-analysis. Diabetologia 56:457–466, 2013 23232641
16 Tuttle KR, Bakris GL, Bilous RW, Chiang JL, de Boer IH, Goldstein-Fuchs J, Hirsch IB, Kalantar-Zadeh K, Narva AS, Navaneethan SD, Neumiller JJ, Patel UD, Ratner RE, Whaley-Connell AT, Molitch ME: Diabetic kidney disease: a report from an ADA Consensus Conference. Diabetes Care 37:2864–2883, 2014 25249672
17 Wolf G, Muller N, Mandecka A, Muller UA: Association of diabetic retinopathy and renal function in patients with types 1 and 2 diabetes mellitus. Clin Nephrol 68:81–86, 2007 17722706
18 Levey AS, de Jong PE, Coresh J, El Nahas M, Astor BC, Matsushita K, Gansevoort RT, Kasiske BL, Eckardt KU: The definition, classification and prognosis of chronic kidney disease: a KDIGO Controversies Conference report. Kidney Int 80:17–28, 2011 21150873
19 American Diabetes Association: Standards of medical care in diabetes—2017. Diabetes Care 40(Suppl 1):S1–S131, 201727979885
20 Molitch ME: Management of early diabetic nephropathy. Am J Med 102:392–398, 1997 9217622
21 Mogensen CE: Prediction of clinical diabetic nephropathy in IDDM patients. Alternatives to microalbuminuria? Diabetes 39:761–767, 1990 2191882
22 Nelson RG, Knowler WC, Pettitt DJ, Bennett PH: Kidney diseases in diabetes. In Diabetes in America. 2nd ed. Harris MI, Cowie CC, Stern MP, Boyko EJ, Reiber GE, Bennett PH, Eds. Bethesda, MD, National Institutes of Health, NIH Pub No. 95-1468, 1995, p. 349–400
23 Ruggenenti P, Porrini EL, Gaspari F, Motterlini N, Cannata A, Carrara F, Cella C, Ferrari S, Stucchi N, Parvanova A, Iliev I, Dodesini AR, Trevisan R, Bossi A, Zaletel J, Remuzzi G; GFR Study Investigators: Glomerular hyperfiltration and renal disease progression in type 2 diabetes. Diabetes Care 35:2061–2068, 2012 22773704
24 Ficociello LH, Perkins BA, Roshan B, Weinberg JM, Aschengrau A, Warram JH, Krolewski AS: Renal hyperfiltration and the development of microalbuminuria in type 1 diabetes. Diabetes Care 32:889–893, 2009 19196883
25 Thomas MC, Moran JL, Harjutsalo V, Thorn L, Waden J, Saraheimo M, Tolonen N, Leiviska J, Jula A, Forsblom C, Groop PH; FinnDiane Study Group: Hyperfiltration in type 1 diabetes: does it exist and does it matter for nephropathy? Diabetologia 55:1505–1513, 2012 22322918
26 Moriya T, Tsuchiya A, Okizaki S, Hayashi A, Tanaka K, Shichiri M: Glomerular hyperfiltration and increased glomerular filtration surface are associated with renal function decline in normo- and microalbuminuric type 2 diabetes. Kidney Int 81:486–493, 2012 22157655
27 Murussi M, Gross JL, Silveiro SP: Glomerular filtration rate changes in normoalbuminuric and microalbuminuric type 2 diabetic patients and normal individuals. A 10-year follow-up. J Diabetes Complications 20:210–215, 2006 16798471
28 Chaiken RL, Eckert-Norton M, Bard M, Banerji MA, Palmisano J, Sachimechi I, Lebovitz HE: Hyperfiltration in African-American patients with type 2 diabetes. Cross-sectional and longitudinal data. Diabetes Care 21:2129–2134, 1998 9839105
29 Brenner BM, Lawler EV, Mackenzie HS: The hyperfiltration theory: a paradigm shift in nephrology. Kidney Int 49:1774–1777, 1996 8743495
30 Mogensen CE, Christensen CK, Vittinghus E: The stages in diabetic renal disease. With emphasis on the stage of incipient diabetic nephropathy. Diabetes 32(Suppl 2):64–78, 1983 6400670
31 Martin P, Hampton KK, Walton C, Tindall H, Davies JA: Microproteinuria in type 2 diabetes mellitus from diagnosis. Diabet Med 7:315–318, 1990 1692521
32 Mogensen CE: A complete screening of urinary albumin concentration in an unselected diabetic out-patient clinic population. Diabetic Nephropathy 2:11–18, 1983
33 de Boer IH, Rue TC, Cleary PA, Lachin JM, Molitch ME, Steffes MW, Sun W, Zinman B, Brunzell JD; Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Study Research Group, White NH, Danis RP, Davis MD, Hainsworth D, Hubbard LD, Nathan DM: Long-term renal outcomes of patients with type 1 diabetes mellitus and microalbuminuria: an analysis of the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications cohort. Arch Intern Med 171:412–420, 2011 21403038
34 Hovind P, Tarnow L, Rossing P, Jensen BR, Graae M, Torp I, Binder C, Parving HH: Predictors for the development of microalbuminuria and macroalbuminuria in patients with type 1 diabetes: inception cohort study. BMJ 328:1105, 2004 15096438
35 Viberti GC, Walker JD, Pinto JL: Diabetic nephropathy. In International Textbook of Diabetes Mellitus. 1st ed. Alberti KG, DeFronzo RA, Keen H, Zimmet P, Eds. New York, John Wiley & Sons, 1992, p. 1267–1328
36 Perkins BA, Ficociello LH, Silva KH, Finkelstein DM, Warram JH, Krolewski AS: Regression of microalbuminuria in type 1 diabetes. N Engl J Med 348:2285–2293, 2003 12788992
37 Parving HH, Mauer M, Fioretto P, Rossing P, Ritz E: Diabetic nephropathy. In Brenner & Rector’s The Kidney. 9th ed. Taal MW, Chertow GM, Marsden PA, Skorecki K, Yu AS, Brenner BM, Eds. Philadelphia, Saunders Elsevier, 2011, p. 1411–1443
38 Mogensen CE, Poulsen PL: Epidemiology of microalbuminuria in diabetes and in the background population. Curr Opin Nephrol Hypertens 3:248–256, 1994 7922249
39 Jerums G, Panagiotopoulos S, Premaratne E, MacIsaac RJ: Integrating albuminuria and GFR in the assessment of diabetic nephropathy. Nat Rev Nephrol 5:397–406, 2009 19556994
40 Parving HH, Gall MA, Skott P, Jorgensen HE, Lokkegaard H, Jorgensen F, Nielsen B, Larsen S: Prevalence and causes of albuminuria in non-insulin-dependent diabetic patients. Kidney Int 41:758–762, 1992 1513098
41 Sharma SG, Bomback AS, Radhakrishnan J, Herlitz LC, Stokes MB, Markowitz GS, D’Agati VD: The modern spectrum of renal biopsy findings in patients with diabetes. Clin J Am Soc Nephrol 8:1718–1724, 2013 23886566
42 Lindeman RD: Overview: renal physiology and pathophysiology of aging. Am J Kidney Dis 16:275–282, 1990 2220770
43 Tan JC, Busque S, Workeneh B, Ho B, Derby G, Blouch KL, Sommer FG, Edwards B, Myers BD: Effects of aging on glomerular function and number in living kidney donors. Kidney Int 78:686–692, 2010 20463656
44 Hoang K, Tan JC, Derby G, Blouch KL, Masek M, Ma I, Lemley KV, Myers BD: Determinants of glomerular hypofiltration in aging humans. Kidney Int 64:1417–1424, 2003 12969161
45 Hostetter TH, Rennke HG, Brenner BM: The case for intrarenal hypertension in the initiation and progression of diabetic and other glomerulopathies. Am J Med 72:375–380, 1982 7036732
46 Ditzel J, Schwartz M: Abnormally increased glomerular filtration rate in short-term insulin-treated diabetic subjects. Diabetes 16:264–267, 1967 6023168
47 Brochner-Mortensen J: Glomerular filtration rate and extracellular fluid volumes during normoglycemia and moderate hyperglycemia in diabetics. Scand J Clin Lab Invest 32:311–316, 1973 4203766
48 Hostetter TH, Troy JL, Brenner BM: Glomerular hemodynamics in experimental diabetes mellitus. Kidney Int 19:410–415, 1981 7241881
49 Mogensen CE: Kidney function and glomerular permeability to macromolecules in early juvenile diabetes. Scand J Clin Lab Invest 28:79–90, 1971 5093522
50 Christiansen JS, Gammelgaard J, Frandsen M, Parving HH: Increased kidney size, glomerular filtration rate and renal plasma flow in short-term insulin-dependent diabetics. Diabetologia 20:451–456, 1981 7016638
51 Vora JP, Dolben J, Dean JD, Thomas D, Williams JD, Owens DR, Peters JR: Renal hemodynamics in newly presenting non-insulin dependent diabetes mellitus. Kidney Int 41:829–835, 1992 1513105
52 Cherney DZ, Scholey JW, Miller JA: Insights into the regulation of renal hemodynamic function in diabetic mellitus. Curr Diabetes Rev 4:280–290, 2008 18991597
53 Vervoort G, Veldman B, Berden JH, Smits P, Wetzels JF: Glomerular hyperfiltration in type 1 diabetes mellitus results from primary changes in proximal tubular sodium handling without changes in volume expansion. Eur J Clin Invest 35:330–336, 2005 15860045
54 Persson P, Hansell P, Palm F: Tubular reabsorption and diabetes-induced glomerular hyperfiltration. Acta Physiol (Oxf) 200:3–10, 2010 20518753
55 Keller CK, Bergis KH, Fliser D, Ritz E: Renal findings in patients with short-term type 2 diabetes. J Am Soc Nephrol 7:2627–2635, 1996 8989741
56 Myers BD, Nelson RG, Williams GW, Bennett PH, Hardy SA, Berg RL, Loon N, Knowler WC, Mitch WE: Glomerular function in Pima Indians with noninsulin-dependent diabetes mellitus of recent onset. J Clin Invest 88:524–530, 1991 1864963
57 Mauer M, Drummond K; International Diabetic Nephropathy Study Group: The early natural history of nephropathy in type 1 diabetes: I. Study design and baseline characteristics of the study participants. Diabetes 51:1572–1579, 2002 11978658
58 Caramori ML, Gross JL, Pecis M, de Azevedo MJ: Glomerular filtration rate, urinary albumin excretion rate, and blood pressure changes in normoalbuminuric normotensive type 1 diabetic patients: an 8-year follow-up study. Diabetes Care 22:1512–1516, 1999 10480518
59 Jerums G, Premaratne E, Panagiotopoulos S, MacIsaac RJ: The clinical significance of hyperfiltration in diabetes. Diabetologia 53:2093–2104, 2010 20496053
60 Magee GM, Bilous RW, Cardwell CR, Hunter SJ, Kee F, Fogarty DG: Is hyperfiltration associated with the future risk of developing diabetic nephropathy? A meta-analysis. Diabetologia 52:691–697, 2009 19198800
61 Wesson DE: Moving closer to an understanding of the hyperfiltration of type 2 diabetes mellitus. Am J Physiol Regul Integr Comp Physiol 290:R973–R974, 2006 16537822
62 Levine DZ, Iacovitti M, Robertson SJ, Mokhtar GA: Modulation of single-nephron GFR in the db/db mouse model of type 2 diabetes mellitus. Am J Physiol Regul Integr Comp Physiol 290:R975–R981, 2006 16339386
63 Lervang HH, Jensen S, Brochner-Mortensen J, Ditzel J: Early glomerular hyperfiltration and the development of late nephropathy in type 1 (insulin-dependent) diabetes mellitus. Diabetologia 31:723–729, 1988 3071482
64 Sasson AN, Cherney DZ: Renal hyperfiltration related to diabetes mellitus and obesity in human disease. World J Diabetes 3:1–6, 2012 22253940
65 Melsom T, Mathisen UD, Ingebretsen OC, Jenssen TG, Njolstad I, Solbu MD, Toft I, Eriksen BO: Impaired fasting glucose is associated with renal hyperfiltration in the general population. Diabetes Care 34:1546–1551, 2011 21593291
66 Mogensen CE, Andersen MJ: Increased kidney size and glomerular filtration rate in untreated juvenile diabetes: normalization by insulin-treatment. Diabetologia 11:221–224, 1975 1149954
67 Christiansen JS, Gammelgaard J, Tronier B, Svendsen PA, Parving HH: Kidney function and size in diabetics before and during initial insulin treatment. Kidney Int 21:683–688, 1982 7050506
68 Schmitz A, Hansen HH, Christensen T: Kidney function in newly diagnosed type 2 (non-insulin-dependent) diabetic patients, before and during treatment. Diabetologia 32:434–439, 1989 2806767
69 Garcia Puig J, Mateos Anton F, Grande C, Pallardo LF, Arnalich F, Gil A, Vasquez JJ, Montero Garcia A: Relation of kidney size to kidney function in early insulin-dependent diabetes. Diabetologia 21:363–367, 1981 7286496
70 Vora JP, Dolben J, Williams JD, Peters JR, Owens DR: Impact of initial treatment on renal function in newly-diagnosed type 2 (non-insulin-dependent) diabetes mellitus. Diabetologia 36:734–740, 1993 8405740
71 Mogensen CE, Andersen MJ: Increased kidney size and glomerular filtration rate in early juvenile diabetes. Diabetes 22:706–712, 1973 4728209
72 Lemley KV, Abdullah I, Myers BD, Meyer TW, Blouch K, Smith WE, Bennett PH, Nelson RG: Evolution of incipient nephropathy in type 2 diabetes mellitus. Kidney Int 58:1228–1237, 2000 10972685
73 Lemley KV, Boothroyd DB, Blouch KL, Nelson RG, Jones LI, Olshen RA, Myers BD: Modeling GFR trajectories in diabetic nephropathy. Am J Physiol Renal Physiol 289:F863–F870, 2005 15900022
74 Christensen CK, Mogensen CE: The course of incipient diabetic nephropathy: studies of albumin excretion and blood pressure. Diabet Med 2:97–102, 1985 2952409
75 Nelson RG, Bennett PH, Williams GW, Berg RL, Hardy SA, Knowler WC, Mitch WE, Myers BD; Diabetic Renal Disease Study: Glomerular function in Pima Indians with type 2 (non-insulin-dependent) diabetes. Diabetologia 33(Suppl):A48, 1990
76 Schmitz A, Christensen T, Moller A, Mogensen CE: Kidney function and cardiovascular risk factors in non-insulin-dependent diabetics (NIDDM) with microalbuminuria. J Intern Med 228:347–352, 1990 2266344
77 Nelson RG, Beck GJ, Myers BD: Course of glomerular injury in Pima Indians with early diabetic nephropathy. J Am Soc Nephrol 4:306, 1993
78 Pavkov ME, Knowler WC, Mason CC, Lemley KV, Myers BD, Nelson RG: Early renal function decline in type 2 diabetes. Clin J Am Soc Nephrol 7:78–84, 2012 22076874
79 Skupien J, Warram JH, Smiles AM, Niewczas MA, Gohda T, Pezzolesi MG, Cantarovich D, Stanton R, Krolewski AS: The early decline in renal function in patients with type 1 diabetes and proteinuria predicts the risk of end-stage renal disease. Kidney Int 82:589–597, 2012 22622493
80 Perkins BA, Ficociello LH, Roshan B, Warram JH, Krolewski AS: In patients with type 1 diabetes and new-onset microalbuminuria the development of advanced chronic kidney disease may not require progression to proteinuria. Kidney Int 77:57–64, 2010 19847154
81 Mauer SM, Steffes MW, Chern M, Brown DM: Mesangial uptake and processing of macromolecules in rats with diabetes mellitus. Lab Invest 41:401–406, 1979 502472
82 Viberti GC, Macintosh D, Bilous RW, Pickup JC, Keen H: Proteinuria in diabetes mellitus: role of spontaneous and experimental variation of glycemia. Kidney Int 21:714–720, 1982 7050509
83 Kaysen GA, Myers BD, Couser WG, Rabkin R, Felts JM: Mechanisms and consequences of proteinuria. Lab Invest 54:479–498, 1986 3517485
84 Brenner BM, Hostetter TH, Humes HD: Glomerular permselectivity: barrier function based on discrimination of molecular size and charge. Am J Physiol 234:F455–F460, 1978 665772
85 Mauer MS, Steffes MW, Ellis EN, Sutherland DE, Brown DM, Goetz FC: Structural-functional relationships in diabetic nephropathy. J Clin Invest 74:1143–1155, 1984 6480821
86 Qian Y, Feldman E, Pennathur S, Kretzler M, Brosius FC, 3rd: From fibrosis to sclerosis: mechanisms of glomerulosclerosis in diabetic nephropathy. Diabetes 57:1439–1445, 2008 18511444
87 Anderson S, Vora JP: Current concepts of renal hemodynamics in diabetes. J Diabetes Complications 9:304–307, 1995 8573753
88 Kanwar YS, Wada J, Sun L, Xie P, Wallner EI, Chen S, Chugh S, Danesh FR: Diabetic nephropathy: mechanisms of renal disease progression. Exp Biol Med (Maywood) 233:4–11, 2008 18156300
89 Steinke JM, Sinaiko AR, Kramer MS, Suissa S, Chavers BM, Mauer M; International Diabetic Nephropathy Study Group: The early natural history of nephropathy in type 1 diabetes: III. Predicators of 5-year urinary albumin excretion rate patterns in initially normoalbuminuric patients. Diabetes 54:2164–2171, 2005 15983218
90 Perrin NE, Torbjornsdotter T, Jaremko GA, Berg UB: Risk markers of future microalbuminuria and hypertension based on clinical and morphological parameters in young type 1 diabetes patients. Pediatr Diabetes 11:305–313, 2010 19761528
91 Caramori ML, Parks A, Mauer M: Renal lesions predict progression of diabetic nephropathy in type 1 diabetes. J Am Soc Nephrol 24:1175–1181, 2013 23687360
92 Fioretto P, Mauer M, Brocco E, Velussi M, Frigato F, Muollo B, Sambataro M, Abaterusso C, Baggio B, Crepaldi G, Nosadini R: Patterns of renal injury in NIDDM patients with microalbuminuria. Diabetologia 39:1569–1576, 1996 8960844
93 Osterby R, Gall MA, Schmitz A, Nielsen FS, Nyberg G, Parving HH: Glomerular structure and function in proteinuric type 2 (non-insulin-dependent) diabetic patients. Diabetologia 36:1064–1070, 1993 8243856
94 Nosadini R, Velussi M, Brocco E, Bruseghin M, Abaterusso C, Saller A, Dalla Vestra M, Carraro A, Bortoloso E, Sambataro M, Barzon I, Frigato F, Muollo B, Chiesura-Corona M, Pacini G, Baggio B, Piarulli F, Sfriso A, Fioretto P: Course of renal function in type 2 diabetic patients with abnormalities of albumin excretion rate. Diabetes 49:476–484, 2000 10868971
95 Moriya T, Suzuki Y, Inomata S, Iwano M, Kanauchi M, Haneda M: Renal histological heterogeneity and functional progress in normoalbuminuric and microalbuminuric Japanese patients with type 2 diabetes. BMJ Open Diabetes Res Care 2:e000029, 2014
96 Dane MJ, Khairoun M, Lee DH, van den Berg BM, Eskens BJ, Boels MG, van Teeffelen JW, Rops AL, van der Vlag J, van Zonneveld AJ, Reinders ME, Vink H, Rabelink TJ: Association of kidney function with changes in the endothelial surface layer. Clin J Am Soc Nephrol 9:698–704, 2014 24458084
97 Satchell S: The role of the glomerular endothelium in albumin handling. Nat Rev Nephrol 9:717–725, 2013 24080802
98 Garsen M, Rops AL, Rabelink TJ, Berden JH, van der Vlag J: The role of heparanase and the endothelial glycocalyx in the development of proteinuria. Nephrol Dial Transplant 29:49–55, 2014 24166469
99 Zhang C, Meng Y, Liu Q, Xuan M, Zhang L, Deng B, Zhang K, Liu Z, Lei T: Injury to the endothelial surface layer induces glomerular hyperfiltration rats with early-stage diabetes. J Diabetes Res 2014 Apr 9 [Epub] doi: 10.1155/2014/953740
100 Satchell SC, Braet F: Glomerular endothelial cell fenestrations: an integral component of the glomerular filtration barrier. Am J Physiol Renal Physiol 296:F947–F956, 2009 19129259
101 Ballermann BJ: Contribution of the endothelium to the glomerular permselectivity barrier in health and disease. Nephron Physiol 106:19–25, 2007
102 Weil EJ, Lemley KV, Mason CC, Yee B, Jones LI, Blouch K, Lovato T, Richardson M, Myers BD, Nelson RG: Podocyte detachment and reduced glomerular capillary endothelial fenestration promote kidney disease in type 2 diabetic nephropathy. Kidney Int 82:1010–1017, 2012 22718189
103 Fioretto P, Mauer M: Histopathology of diabetic nephropathy. Semin Nephrol 27:195–207, 2007 17418688
104 Tervaert TW, Mooyaart AL, Amann K, Cohen AH, Cook HT, Drachenberg CB, Ferrario F, Fogo AB, Haas M, de Heer E, Joh K, Noel LH, Radhakrishnan J, Seshan SV, Bajema IM, Bruijn JA; Renal Pathology Society: Pathologic classification of diabetic nephropathy. J Am Soc Nephrol 21:556–563, 2010 20167701
105 Steffes MW, Bilous RW, Sutherland DE, Mauer SM: Cell and matrix components of the glomerular mesangium in type I diabetes. Diabetes 41:679–684, 1992 1587395
106 White KE, Bilous RW; The Collaborative Study Group: Type 2 diabetic patients with nephropathy show structural-functional relationships that are similar to type 1 disease. J Am Soc Nephrol 11:1667–1673, 2000 10966491
107 Caramori ML, Kim Y, Huang C, Fish AJ, Rich SS, Miller ME, Russell G, Mauer M: Cellular basis of diabetic nephropathy: 1. Study design and renal structural-functional relationships in patients with long-standing type 1 diabetes. Diabetes 51:506–513, 2002 11812762
108 Poole G: Intercapillary glomerulosclerosis and the Kimmelstiel-Wilson syndrome. Postgrad Med J 29:137–146, 1953 13055534
109 Najafian B, Alpers CE, Fogo AB: Pathology of human diabetic nephropathy. Contrib Nephrol 170:36–47, 2011 21659756
110 Schwartz MM, Lewis EJ, Leonard-Martin T, Lewis JB, Batlle D: Renal pathology patterns in type II diabetes mellitus: relationship with retinopathy. The Collaborative Study Group. Nephrol Dial Transplant 13:2547–2552, 1998 9794557
111 Osterby R, Parving HH, Hommel E, Jorgensen HE, Lokkegaard H: Glomerular structure and function in diabetic nephropathy. Early to advanced stages. Diabetes 39:1057–1063, 1990 2384188
112 Salmon AH, Toma I, Sipos A, Muston PR, Harper SJ, Bates DO, Neal CR, Peti-Peterdi J: Evidence for restriction of fluid and solute movement across the glomerular capillary wall by the subpodocyte space. Am J Physiol Renal Physiol 293:F1777–F1786, 2007 17804486
113 Kriz W: Progressive renal failure—inability of podocytes to replicate and the consequences for development of glomerulosclerosis. Nephrol Dial Transplant 11:1738–1742, 1996
114 Becker JU, Hoerning A, Schmid KW, Hoyer PF: Immigrating progenitor cells contribute to human podocyte turnover. Kidney Int 72:1468–1473, 2007 17898701
115 Ohse T, Pippin JW, Chang AM, Krofft RD, Miner JH, Vaughan MR, Shankland SJ: The enigmatic parietal epithelial cell is finally getting noticed: a review. Kidney Int 76:1225–1238, 2009 19847153
116 Shankland SJ, Wolf G: Cell cycle regulatory proteins in renal disease: role in hypertrophy, proliferation, and apoptosis. Am J Physiol Renal Physiol 278:F515–F529, 2000 10751212
117 Pagtalunan ME, Miller PL, Jumping-Eagle S, Nelson RG, Myers BD, Rennke HG, Coplon NS, Sun L, Meyer TW: Podocyte loss and progressive glomerular injury in type II diabetes. J Clin Invest 99:342–348, 1997 9006003
118 Sun YB, Qu X, Zhang X, Caruana G, Bertram JF, Li J: Glomerular endothelial cell injury and damage precedes that of podocytes in adriamycin-induced nephropathy. PLOS ONE 8:e55027, 2013 23359116
119 Nakagawa T, Sato W, Glushakova O, Heinig M, Clarke T, Campbell-Thompson M, Yuzawa Y, Atkinson MA, Johnson RJ, Croker B: Diabetic endothelial nitric oxide synthase knockout mice develop advanced diabetic nephropathy. J Am Soc Nephrol 18:539–550, 2007 17202420
120 Yuen DA, Stead BE, Zhang Y, White KE, Kabir MG, Thai K, Advani SL, Connelly KA, Takano T, Zhu L, Cox AJ, Kelly DJ, Gibson IW, Takahashi T, Harris RC, Advani A: eNOS deficiency predisposes podocytes to injury in diabetes. J Am Soc Nephrol 23:1810–1823, 2012 22997257
121 Dane MJ, van den Berg BM, Avramut MC, Faas FG, van der Vlag J, Rops AL, Ravelli RB, Koster BJ, van Zonneveld AJ, Vink H, Rabelink TJ: Glomerular endothelial surface layer acts as a barrier against albumin filtration. Am J Pathol 182:1532–1540, 2013 23518410
122 Morigi M, Buelli S, Angioletti S, Zanchi C, Longaretti L, Zoja C, Galbusera M, Gastoldi S, Mundel P, Remuzzi G, Benigni A: In response to protein load podocytes reorganize cytoskeleton and modulate endothelin-1 gene: implication for permselective dysfunction of chronic nephropathies. Am J Pathol 166:1309–1320, 2005 15855633
123 Torbjornsdotter TB, Perrin NE, Jaremko GA, Berg UB: Widening of foot processes in normoalbuminuric adolescents with type 1 diabetes. Pediatr Nephrol 20:750–758, 2005 15827743
124 Dalla Vestra M, Masiero A, Roiter AM, Saller A, Crepaldi G, Fioretto P: Is podocyte injury relevant in diabetic nephropathy? Studies in patients with type 2 diabetes. Diabetes 52:1031–1035, 2003 12663476
125 Nakamura T, Ushiyama C, Suzuki S, Hara M, Shimada N, Ebihara I, Koide H: Urinary excretion of podocytes in patients with diabetic nephropathy. Nephrol Dial Transplant 15:1379–1383, 2000 10978394
126 Siu B, Saha J, Smoyer WE, Sullivan KA, Brosius FC, 3rd: Reduction in podocyte density as a pathologic feature in early diabetic nephropathy in rodents: prevention by lipoic acid treatment. BMC Nephrol 7:6, 2006 16539708
127 Ronconi E, Sagrinati C, Angelotti ML, Lazzeri E, Mazzinghi B, Ballerini L, Parente E, Becherucci F, Gacci M, Carini M, Maggi E, Serio M, Vannelli GB, Lasagni L, Romagnani S, Romagnani P: Regeneration of glomerular podocytes by human renal progenitors. J Am Soc Nephrol 20:322–332, 2009 19092120
128 Shankland SJ, Anders HJ, Romagnani P: Glomerular parietal epithelial cells in kidney physiology, pathology, and repair. Curr Opin Nephrol Hypertens 22:302–309, 2013 23518463
129 Bohle A, Wehrmann M, Bogenschutz O, Batz C, Muller CA, Muller GA: The pathogenesis of chronic renal failure in diabetic nephropathy. Investigation of 488 cases of diabetic glomerulosclerosis. Pathol Res Pract 187:251–259, 1991 2068008
130 Najafian B, Mauer M: Progression of diabetic nephropathy in type 1 diabetic patients. Diabetes Res Clin Pract 83:1–8, 2009 19070384
131 Stout LC, Kumar S, Whorton EB: Insudative lesions—their pathogenesis and association with glomerular obsolescence in diabetes: a dynamic hypothesis based on single views of advancing human diabetic nephropathy. Hum Pathol 25:1213–1227, 1994 7959667
132 Mauer SM, Lane P, Zhu D, Fioretto P, Steffes MW: Renal structure and function in insulin-dependent diabetes mellitus in man. J Hypertens Suppl 10:S17–S20, 1992
133 Horsfield GI, Lannigan R: Exudative lesions in diabetes mellitus. J Clin Pathol 18:47–53, 1965 14247704
134 Alsaad KO, Herzenberg AM: Distinguishing diabetic nephropathy from other causes of glomerulosclerosis: an update. J Clin Pathol 60:18–26, 2007 17213346
135 Najafian B, Crosson JT, Kim Y, Mauer M: Glomerulotubular junction abnormalities are associated with proteinuria in type 1 diabetes. J Am Soc Nephrol 17(4 Suppl 2):S53–S60, 2006 16565248
136 Garg AX, Kiberd BA, Clark WF, Haynes RB, Clase CM: Albuminuria and renal insufficiency prevalence guides population screening: results from the NHANES III. Kidney Int 61:2165–2175, 2002 12028457
137 Kramer HJ, Nguyen QD, Curhan G, Hsu CY: Renal insufficiency in the absence of albuminuria and retinopathy among adults with type 2 diabetes mellitus. JAMA 289:3273–3277, 2003 12824208
138 MacIsaac RJ, Tsalamandris C, Panagiotopoulos S, Smith TJ, McNeil KJ, Jerums G: Nonalbuminuric renal insufficiency in type 2 diabetes. Diabetes Care 27:195–200, 2004 14693989
139 Caramori ML, Fioretto P, Mauer M: Low glomerular filtration rate in normoalbuminuric type 1 diabetic patients: an indicator of more advanced glomerular lesions. Diabetes 52:1036–1040, 2003 12663477
140 Rigalleau V, Lasseur C, Raffaitin C, Beauvieux MC, Barthe N, Chauveau P, Combe C, Gin H: Normoalbuminuric renal-insufficient diabetic patients: a lower-risk group. Diabetes Care 30:2034–2039, 2007 17485574
141 Kramer CK, Leitao CB, Pinto LC, Silveiro SP, Gross JL, Canani LH: Clinical and laboratory profile of patients with type 2 diabetes with low glomerular filtration rate and normoalbuminuria. Diabetes Care 30:1998–2000, 2007 17468344
142 Rychlik I, Fliser D, Ritz E: Non-diabetic renal disease in type 2 diabetes mellitus. In Nephropathy in Type 2 Diabetes. Ritz E, Rychlik I, Eds. Oxford, U.K., Oxford University Press, 1999, p. 7–88
143 MacIsaac RJ, Panagiotopoulos S, McNeil KJ, Smith TJ, Tsalamandris C, Hao H, Matthews PG, Thomas MC, Power DA, Jerums G: Is nonalbuminuric renal insufficiency in type 2 diabetes related to an increase in intrarenal vascular disease? Diabetes Care 29:1560–1566, 2006 16801579
144 Pavkov ME, Mason CC, Bennett PH, Curtis JM, Knowler WC, Nelson RG: Change in the distribution of albuminuria according to estimated glomerular filtration rate in Pima Indians with type 2 diabetes. Diabetes Care 32:1845–1850, 2009 19592626
145 Bolignano D, Lacquaniti A, Coppolino G, Donato V, Campo S, Fazio MR, Nicocia G, Buemi M: Neutrophil gelatinase-associated lipocalin (NGAL) and progression of chronic kidney disease. Clin J Am Soc Nephrol 4:337–344, 2009 19176795
146 Nielsen SE, Sugaya T, Hovind P, Baba T, Parving HH, Rossing P: Urinary liver-type fatty acid-binding protein predicts progression to nephropathy in type 1 diabetic patients. Diabetes Care 33:1320–1324, 2010 20185732
147 Nielsen SE, Andersen S, Zdunek D, Hess G, Parving HH, Rossing P: Tubular markers do not predict the decline in glomerular filtration rate in type 1 diabetic patients with overt nephropathy. Kidney Int 79:1113–1118, 2011 21270761
148 von Eynatten M, Baumann M, Heemann U, Zdunek D, Hess G, Nawroth PP, Bierhaus A, Humpert PM: Urinary L-FABP and anaemia: distinct roles of urinary markers in type 2 diabetes. Eur J Clin Invest 40:95–102, 2010 19912308
149 Nielsen SE, Hansen HP, Jensen BR, Parving HH, Rossing P: Urinary neutrophil gelatinase-associated lipocalin and progression of diabetic nephropathy in type 1 diabetic patients in a four-year follow-up study. Nephron Clin Pract 118:c130–c135, 2011 21160226
150 Vaidya VS, Niewczas MA, Ficociello LH, Johnson AC, Collings FB, Warram JH, Krolewski AS, Bonventre JV: Regression of microalbuminuria in type 1 diabetes is associated with lower levels of urinary tubular injury biomarkers, kidney injury molecule-1, and N-acetyl-β-D-glucosaminidase. Kidney Int 79:464–470, 2011 20980978
151 Nielsen SE, Reinhard H, Zdunek D, Hess G, Gutierrez OM, Wolf M, Parving HH, Jacobsen PK, Rossing P: Tubular markers are associated with decline in kidney function in proteinuric type 2 diabetic patients. Diabetes Res Clin Pract 97:71–76, 2012 22402306
152 Kim SS, Song SH, Kim IJ, Yang JY, Lee JG, Kwak IS, Kim YK: Clinical implication of urinary tubular markers in the early stage of nephropathy with type 2 diabetic patients. Diabetes Res Clin Pract 97:251–257, 2012 22440044
153 Fu WJ, Li BL, Wang SB, Chen ML, Deng RT, Ye CQ, Liu L, Fang AJ, Xiong SL, Wen S, Tang HH, Chen ZX, Huang ZH, Peng LF, Zheng L, Wang Q: Changes of the tubular markers in type 2 diabetes mellitus with glomerular hyperfiltration. Diabetes Res Clin Pract 95:105–109, 2012 22015481
154 Conway BR, Manoharan D, Manoharan D, Jenks S, Dear JW, McLachlan S, Strachan MW, Price JF: Measuring urinary tubular biomarkers in type 2 diabetes does not add prognostic value beyond established risk factors. Kidney Int 82:812–818, 2012 22718188
155 Liu KD, Yang W, Anderson AH, Feldman HI, Demirjian S, Hamano T, He J, Lash J, Lustigova E, Rosas SE, Simonson MS, Tao K, Hsu CY; Chronic Renal Insufficiency Cohort (CRIC) study investigators: Urine neutrophil gelatinase-associated lipocalin levels do not improve risk prediction of progressive chronic kidney disease. Kidney Int 83:909–914, 2013 23344473
156 Araki S, Haneda M, Koya D, Sugaya T, Isshiki K, Kume S, Kashiwagi A, Uzu T, Maegawa H: Predictive effects of urinary liver-type fatty acid-binding protein for deteriorating renal function and incidence of cardiovascular disease in type 2 diabetic patients without advanced nephropathy. Diabetes Care 36:1248–1253, 2013 23223350
157 O’Seaghdha CM, Hwang SJ, Larson MG, Meigs JB, Vasan RS, Fox CS: Analysis of a urinary biomarker panel for incident kidney disease and clinical outcomes. J Am Soc Nephrol 24:1880–1888, 2013 23990678
158 Chou KM, Lee CC, Chen CH, Sun CY: Clinical value of NGAL, L-FABP and albuminuria in predicting GFR decline in type 2 diabetes mellitus patients. PLOS ONE 8:e54863, 2013 23349979
159 Panduru NM, Forsblom C, Saraheimo M, Thorn L, Bierhaus A, Humpert PM, Groop PH; FinnDiane Study Group: Urinary liver-type fatty acid-binding protein and progression of diabetic nephropathy in type 1 diabetes. Diabetes Care 36:2077–2083, 2013 23378622
160 Kamijo-Ikemori A, Sugaya T, Yasuda T, Kawata T, Ota A, Tatsunami S, Kaise R, Ishimitsu T, Tanaka Y, Kimura K: Clinical significance of urinary liver-type fatty acid-binding protein in diabetic nephropathy of type 2 diabetic patients. Diabetes Care 34:691–696, 2011 21273494
161 Fufaa GD, Weil EJ, Nelson RG, Hanson RL, Bonventre JV, Sabbisetti V, Waikar SS, Mifflin TE, Zhang X, Xie D, Hsu CY, Feldman HI, Coresh J, Vasan RS, Kimmel PL, Liu KD; Chronic Kidney Disease Biomarkers Consortium Investigators: Association of urinary KIM-1, L-FABP, NAG and NGAL with incident end-stage renal disease and mortality in American Indians with type 2 diabetes mellitus. Diabetologia 58:188–198, 2015 25316431
162 Aksun SA, Ozmen D, Ozmen B, Parildar Z, Mutaf I, Turgan N, Habif S, Kumanliogluc K, Bayindir O: Beta2-microglobulin and cystatin C in type 2 diabetes: assessment of diabetic nephropathy. Exp Clin Endocrinol Diabetes 112:195–200, 2004 15127324
163 Viberti GC, Keen H, Mackintosh D: Beta 2-microglobulinaemia: a sensitive index of diminishing renal function in diabetics. Br Med J (Clin Res Ed) 282:95–98, 1981
164 Astor BC, Shafi T, Hoogeveen RC, Matsushita K, Ballantyne CM, Inker LA, Coresh J: Novel markers of kidney function as predictors of ESRD, cardiovascular disease, and mortality in the general population. Am J Kidney Dis 59:653–662, 2012 22305758
165 Miyazawa I, Araki S, Obata T, Yoshizaki T, Morino K, Kadota A, Ugi S, Kawai H, Uzu T, Nishio Y, Koya D, Haneda M, Kashiwagi A, Maegawa H: Association between serum soluble TNFα receptors and renal dysfunction in type 2 diabetic patients without proteinuria. Diabetes Res Clin Pract 92:174–180, 2011 21288590
166 Lopes-Virella MF, Baker NL, Hunt KJ, Cleary PA, Klein R, Virella G; DCCT/EDIC Research Group: Baseline markers of inflammation are associated with progression to macroalbuminuria in type 1 diabetic subjects. Diabetes Care 36:2317–2323, 2013 23514730
167 Niewczas MA, Ficociello LH, Johnson AC, Walker W, Rosolowsky ET, Roshan B, Warram JH, Krolewski AS: Serum concentrations of markers of TNFalpha and Fas-mediated pathways and renal function in nonproteinuric patients with type 1 diabetes. Clin J Am Soc Nephrol 4:62–70, 2009 19073786
168 Niewczas MA, Gohda T, Skupien J, Smiles AM, Walker WH, Rosetti F, Cullere X, Eckfeldt JH, Doria A, Mayadas TN, Warram JH, Krolewski AS: Circulating TNF receptors 1 and 2 predict ESRD in type 2 diabetes. J Am Soc Nephrol 23:507–515, 2012 22266663
169 Gohda T, Niewczas MA, Ficociello LH, Walker WH, Skupien J, Rosetti F, Cullere X, Johnson AC, Crabtree G, Smiles AM, Mayadas TN, Warram JH, Krolewski AS: Circulating TNF receptors 1 and 2 predict stage 3 CKD in type 1 diabetes. J Am Soc Nephrol 23:516–524, 2012 22266664
170 Forsblom C, Moran J, Harjutsalo V, Loughman T, Waden J, Tolonen N, Thorn L, Saraheimo M, Gordin D, Groop PH, Thomas MC; FinnDiane Study Group: Added value of soluble tumor necrosis factor-α receptor 1 as a biomarker of ESRD risk in patients with type 1 diabetes. Diabetes Care 37:2334–2342, 2014 24879837
171 Saulnier PJ, Gand E, Ragot S, Ducrocq G, Halimi JM, Hulin-Delmotte C, Llaty P, Montaigne D, Rigalleau V, Roussel R, Velho G, Sosner P, Zaoui P, Hadjadj S; SURDIAGENE Study Group: Association of serum concentration of TNFR1 with all-cause mortality in patients with type 2 diabetes and chronic kidney disease: follow-up of the SURDIAGENE Cohort. Diabetes Care 37:1425–1431, 2014 24623026
172 Pavkov ME, Nelson RG, Knowler WC, Cheng Y, Krolewski AS, Niewczas MA: Elevation of circulating TNF receptors 1 and 2 increases the risk of end-stage renal disease in American Indians with type 2 diabetes. Kidney Int 87:812–819, 2015 25272234
173 Yao Y, Rabodzey A, Dewey CF, Jr.: Glycocalyx modulates the motility and proliferative response of vascular endothelium to fluid shear stress. Am J Physiol Heart Circ Physiol 293:H1023–H1030, 2007 17468337
174 Jeansson M, Bjorck K, Tenstad O, Haraldsson B: Adriamycin alters glomerular endothelium to induce proteinuria. J Am Soc Nephrol 20:114–122, 2009 19073829
175 Wahl P, Deppermann D, Hasslacher C: Biochemistry of glomerular basement membrane of the normal and diabetic human. Kidney Int 21:744–749, 1982 7109461
176 Vernier RL, Steffes MW, Sisson-Ross S, Mauer SM: Heparan sulfate proteoglycan in the glomerular basement membrane in type 1 diabetes mellitus. Kidney Int 41:1070–1080, 1992 1513088
177 Alfino PA, Neugarten J, Schacht RG, Dworkin LD, Baldwin DS: Glomerular size-selective barrier dysfunction in nephrotoxic serum nephritis. Kidney Int 34:151–155, 1988 2460659
178 Andersson M, Nilsson U, Hjalmarsson C, Haraldsson B, Nystrom JS: Mild renal ischemia-reperfusion reduces charge and size selectivity of the glomerular barrier. Am J Physiol Renal Physiol 292:F1802–F1809, 2007 17376766
179 Bennett CM, Glassock RJ, Chang RL, Deen WM, Robertson CR, Brenner BM, Troy JL, Ueki IR, Rasmussen B: Permselectivity of the glomerular capillary wall. Studies of experimental glomerulonephritis in the rat using dextran sulfate. J Clin Invest 57:1287–1294, 1976 1262472
180 Blouch K, Deen WM, Fauvel JP, Bialek J, Derby G, Myers BD: Molecular configuration and glomerular size selectivity in healthy and nephrotic humans. Am J Physiol 273:F430–F437, 1997 9321916
181 Fox JG, Quin JD, Paterson KR, O’Reilly DS, Smith MP, Boulton-Jones JM: Glomerular charge selectivity in type 1 (insulin-dependent) diabetes mellitus. Diabet Med 12:387–391, 1995 7648799
182 Groggel GC, Stevenson J, Hovingh P, Linker A, Border WA: Changes in heparan sulfate correlate with increased glomerular permeability. Kidney Int 33:517–523, 1988 2452273
183 Guasch A, Myers BD: Determinants of glomerular hypofiltration in nephrotic patients with minimal change nephropathy. J Am Soc Nephrol 4:1571–1581, 1994 8025231
184 Myers BD, Winetz JA, Chui F, Michaels AS: Mechanisms of proteinuria in diabetic nephropathy: a study of glomerular barrier function. Kidney Int 21:633–641, 1982 6178872
185 Oliver JD, 3rd, Anderson S, Troy JL, Brenner BM, Deen WM: Determination of glomerular size-selectivity in the normal rat with Ficoll. J Am Soc Nephrol 3:214–228, 1992 1382654
186 Olson JL, Hostetter TH, Rennke HG, Brenner BM, Venkatachalam MA: Altered glomerular permselectivity and progressive sclerosis following extreme ablation of renal mass. Kidney Int 22:112–126, 1982 6182335
187 Olson JL, Rennke HG, Venkatachalam MA: Alterations in the charge and size selectivity barrier of the glomerular filter in aminonucleoside nephrosis in rats. Lab Invest 44:271–279, 1981 7464051
188 Ruggenenti P, Mosconi L, Sangalli F, Casiraghi F, Gambara V, Remuzzi G, Remuzzi A: Glomerular size selective dysfunction in NIDDM is not ameliorated by ACE inhibition or by calcium channel blockade. Kidney Int 55:984–994, 1999 10027935
189 Scandling JD, Black VM, Deen WM, Myers BD: Glomerular permselectivity in healthy and nephrotic humans. Adv Nephrol Necker Hosp 21:159–176, 1992 1566645
190 Scandling JD, Myers BD: Glomerular size-selectivity and microalbuminuria in early diabetic glomerular disease. Kidney Int 41:840–846, 1992 1381005
191 Haraldsson B, Sorensson J: Why do we not all have proteinuria? An update of our current understanding of the glomerular barrier. News Physiol Sci 19:7–10, 2004 14739395
192 Singh A, Satchell SC, Neal CR, McKenzie EA, Tooke JE, Mathieson PW: Glomerular endothelial glycocalyx constitutes a barrier to protein permeability. J Am Soc Nephrol 18:2885–2893, 2007 17942961
193 Singh A, Friden V, Dasgupta I, Foster RR, Welsh GI, Tooke JE, Haraldsson B, Mathieson PW, Satchell SC: High glucose causes dysfunction of the human glomerular endothelial glycocalyx. Am J Physiol Renal Physiol 300:F40–F48, 2011 20980411
194 Lemley KV, Blouch K, Abdullah I, Boothroyd DB, Bennett PH, Myers BD, Nelson RG: Glomerular permselectivity at the onset of nephropathy in type 2 diabetes mellitus. J Am Soc Nephrol 11:2095–2105, 2000 11053486
195 Deckert T, Kofoed-Enevoldsen A, Vidal P, Norgaard K, Andreasen HB, Feldt-Rasmussen B: Size- and charge selectivity of glomerular filtration in type 1 (insulin-dependent) diabetic patients with and without albuminuria. Diabetologia 36:244–251, 1993 8462774
196 Friedman S, Jones HW, III, Golbetz HV, Lee JA, Little HL, Myers BD: Mechanisms of proteinuria in diabetic nephropathy II: a study of the size-selective glomerular filtration barrier. Diabetes 32(Suppl 2):40–46, 1983 6086024
197 Myers BD, Nelson RG, Bennett PH, Mitch WE; Diabetic Renal Disease Study: Glomerular function at onset of nephropathy in NIDDM (Abstract). J Am Soc Nephrol 2:A295, 1991
198 Tomlanovich S, Deen WM, Jones HW, 3rd, Schwartz HC, Myers BD: Functional nature of glomerular injury in progressive diabetic glomerulopathy. Diabetes 36:556–565, 1987 2436961
199 Pavenstadt H, Kriz W, Kretzler M: Cell biology of the glomerular podocyte. Physiol Rev 83:253–307, 2003 12506131
200 Peti-Peterdi J: Independent two-photon measurements of albumin GSC give low values. Am J Physiol Renal Physiol 296:F1255–F1257, 2009 19297453
201 Russo LM, Sandoval RM, Campos SB, Molitoris BA, Comper WD, Brown D: Impaired tubular uptake explains albumin-uria in early diabetic nephropathy. J Am Soc Nephrol 20:489–494, 2009 19118149
202 Comper WD, Hilliard LM, Nikolic-Paterson DJ, Russo LM: Disease-dependent mechanisms of albuminuria. Am J Physiol Renal Physiol 295:F1589–F1600, 2008 18579704
203 Peti-Peterdi J, Burford JL, Hackl MJ: The first decade of using multiphoton microscopy for high-power kidney imaging. Am J Physiol Renal Physiol 302:F227–F233, 2012 22031850
204 Tanner GA, Rippe C, Shao Y, Evan AP, Williams JC, Jr.: Glomerular permeability to macromolecules in the Necturus kidney. Am J Physiol Renal Physiol 296:F1269–F1278, 2009 19339627
205 Tanner GA: Glomerular sieving coefficient of serum albumin in the rat: a two-photon microscopy study. Am J Physiol Renal Physiol 296:F1258–F1265, 2009 19211688
206 Keen H, Chlouverakis C, Fuller J, Jarrett RJ: The concomitants of raised blood sugar: studies in newly detected hyper-glycemics. II. Urinary albumin excretion, blood pressure and their relation to blood sugar levels. Guys Hosp Rep 118:247–254, 1969 5804067
207 Nelson RG, Kunzelman CL, Pettitt DJ, Saad MF, Bennett PH, Knowler WC: Albuminuria in type 2 (non-insulin-dependent) diabetes mellitus and impaired glucose tolerance in Pima Indians. Diabetologia 32:870–876, 1989 2612758
208 Collins VR, Dowse GK, Finch CF, Zimmet PZ, Linnane AW: Prevalence and risk factors for micro- and macroalbuminuria in diabetic subjects and entire population of Nauru. Diabetes 38:1602–1610, 1989 2583379
209 Saydah SH, Pavkov ME, Zhang C, Lacher DA, Eberhardt MS, Burrows NR, Narva AS, Eggers PW, Williams DE: Albuminuria prevalence in first morning void compared with previous random urine from adults in the National Health and Nutrition Examination Survey, 2009–2010. Clin Chem 59:675–683, 2013 23315482
210 Claudi T, Cooper JG: Comparison of urinary albumin excretion rate in overnight urine and albumin creatinine ratio in spot urine in diabetic patients in general practice. Scand J Prim Health Care 19:247–248, 2001 11822649
211 Gansevoort RT, Verhave JC, Hillege HL, Burgerhof JG, Bakker SJ, de Zeeuw D, de Jong PE; PREVEND Study Group: The validity of screening based on spot morning urine samples to detect subjects with microalbuminuria in the general population. Kidney Int Suppl 94:S28–S35, 2005
212 Howey JE, Browning MC, Fraser CG: Biologic variation of urinary albumin: consequences for analysis, specimen collection, interpretation of results, and screening programs. Am J Kidney Dis 13:35–37, 1989 2912063
213 Afkarian M, Zelnick LR, Hall YN, Heagerty PJ, Tuttle K, Weiss NS, de Boer IH: Clinical manifestations of kidney disease among US adults with diabetes, 1988–2014. JAMA 316:602–610, 2016 27532915
214 Menke A, Orchard TJ, Imperatore G, Bullard KM, Mayer-Davis E, Cowie CC: The prevalence of type 1 diabetes in the United States. Epidemiology 24:773–774, 2013 23903880
215 Costacou T, Fried L, Ellis D, Orchard TJ: Sex differences in the development of kidney disease in individuals with type 1 diabetes mellitus: a contemporary analysis. Am J Kidney Dis 58:565–573, 2011 21840097
216 Klein R, Klein BE, Linton KL, Moss SE: Microalbuminuria in a population-based study of diabetes. Arch Intern Med 152:153–158, 1992 1728911
217 Groop PH, Thomas MC, Moran JL, Waden J, Thorn LM, Makinen VP, Rosengard-Barlund M, Saraheimo M, Hietala K, Heikkila O, Forsblom C; FinnDiane Study Group: The presence and severity of chronic kidney disease predicts all-cause mortality in type 1 diabetes. Diabetes 58:1651–1658, 2009 19401416
218 Parving HH, Hommel E, Mathiesen E, Skott P, Edsberg B, Bahnsen M, Lauritzen M, Hougaard P, Lauritzen E: Prevalence of microalbuminuria, arterial hypertension, retinopathy and neuropathy in patients with insulin dependent diabetes. Br Med J (Clin Res Ed) 296:156–160, 1988
219 Skrivarhaug T, Bangstad HJ, Stene LC, Sandvik L, Hanssen KF, Joner G: Low risk of overt nephropathy after 24 yr of childhood-onset type 1 diabetes mellitus (T1DM) in Norway. Pediatr Diabetes 7:239–246, 2006 17054444
220 Eeg-Olofsson K, Cederholm J, Nilsson PM, Zethelius B, Svensson AM, Gudbjornsdottir S, Eliasson B: Glycemic control and cardiovascular disease in 7,454 patients with type 1 diabetes: an observational study from the Swedish National Diabetes Register (NDR). Diabetes Care 33:1640–1646, 2010 20424222
221 Raile K, Galler A, Hofer S, Herbst A, Dunstheimer D, Busch P, Holl RW: Diabetic nephropathy in 27,805 children, adolescents, and adults with type 1 diabetes: effect of diabetes duration, A1C, hypertension, dyslipidemia, diabetes onset, and sex. Diabetes Care 30:2523–2528, 2007 17630266
222 Parving HH, Lewis JB, Ravid M, Remuzzi G, Hunsicker LG; DEMAND investigators: Prevalence and risk factors for microalbuminuria in a referred cohort of type II diabetic patients: a global perspective. Kidney Int 69:2057–2063, 2006 16612330
223 Mogensen CE, Christensen CK: Predicting diabetic nephropathy in insulin-dependent patients. N Engl J Med 311:89–93, 1984 6738599
224 Viberti GC, Jarrett RJ, Mahmud U, Hill RD, Argyropoulos A, Keen H: Microalbuminuria as a predictor of clinical nephropathy in insulin-dependent diabetes mellitus. Lancet 1:1430–1432, 1982 6123720
225 Parving HH, Oxenboll B, Svendsen PA, Christiansen JS, Andersen AR: Early detection of patients at risk of developing diabetic nephropathy. A longitudinal study of urinary albumin excretion. Acta Endocrinol (Copenh) 100:550–555, 1982 6812342
226 Mathiesen ER, Oxenboll B, Johansen K, Svendsen PA, Deckert T: Incipient nephropathy in type 1 (insulin-dependent) diabetes. Diabetologia 26:406–410, 1984 6468791
227 Messent JW, Elliott TG, Hill RD, Jarrett RJ, Keen H, Viberti GC: Prognostic significance of microalbuminuria in insulin-dependent diabetes mellitus: a twenty-three year follow-up study. Kidney Int 41:836–839, 1992 1513106
228 Mogensen CE: Microalbuminuria predicts clinical proteinuria and early mortality in maturity-onset diabetes. N Engl J Med 310:356–360, 1984 6690964
229 Jerums G, Cooper ME, Seeman E, Murray RM, McNeil JJ: Spectrum of proteinuria in type I and type II diabetes. Diabetes Care 10:419–427, 1987 3622199
230 Nelson RG, Knowler WC, Pettitt DJ, Saad MF, Charles MA, Bennett PH: Assessment of risk of overt nephropathy in diabetic patients from albumin excretion in untimed urine specimens. Arch Intern Med 151:1761–1765, 1991 1888242
231 Johns L, Rao PS, Kanagasabapathy AS: Rate of progression of albuminuria in type II diabetes. Five-year prospective study from South India. Diabetes Care 17:888–890, 1994 7956637
232 Andersen AR, Christiansen JS, Andersen JK, Kreiner S, Deckert T: Diabetic nephropathy in type 1 (insulin-dependent) diabetes: an epidemiological study. Diabetologia 25:496–501, 1983 6363177
233 Klein R, Klein BE, Moss SE: The incidence of gross proteinuria in people with insulin-dependent diabetes mellitus. Arch Intern Med 151:1344–1348, 1991 2064485
234 Noth RH, Krolewski AS, Kaysen GA, Meyer TW, Schambelan M: Diabetic nephropathy: hemodynamic basis and implications for disease management. Ann Intern Med 110:795–813, 1989 2653154
235 Rossing P, Hougaard P, Parving HH: Progression of microalbuminuria in type 1 diabetes: ten-year prospective observational study. Kidney Int 68:1446–1450, 2005 16164620
236 Ballard DJ, Humphrey LL, Melton LJ, 3rd, Frohnert PP, Chu PC, O’Fallon WM, Palumbo PJ: Epidemiology of persistent proteinuria in type II diabetes mellitus. Population-based study in Rochester, Minnesota. Diabetes 37:405–412, 1988 3378684
237 Klein R, Klein BE, Moss SE: Incidence of gross proteinuria in older-onset diabetes. A population-based perspective. Diabetes 42:381–389, 1993 8432408
238 Kunzelman CL, Knowler WC, Pettitt DJ, Bennett PH: Incidence of proteinuria in type 2 diabetes mellitus in the Pima Indians. Kidney Int 35:681–687, 1989 2785225
239 Krolewski AS, Warram JH, Christlieb AR, Busick EJ, Kahn CR: The changing natural history of nephropathy in type I diabetes. Am J Med 78:785–794, 1985 3993659
240 Kofoed-Enevoldsen A, Borch-Johnsen K, Kreiner S, Nerup J, Deckert T: Declining incidence of persistent proteinuria in type I (insulin-dependent) diabetic patients in Denmark. Diabetes 36:205–209, 1987 3803732
241 Pambianco G, Costacou T, Ellis D, Becker DJ, Klein R, Orchard TJ: The 30-year natural history of type 1 diabetes complications: the Pittsburgh Epidemiology of Diabetes Complications Study experience. Diabetes 55:1463–1469, 2006 16644706
242 Bojestig M, Arnqvist HJ, Hermansson G, Karlberg BE, Ludvigsson J: Declining incidence of nephropathy in insulin-dependent diabetes mellitus. N Engl J Med 330:15–18, 1994 8259139
243 Rossing P: The changing epidemiology of diabetic microangiopathy in type 1 diabetes. Diabetologia 48:1439–1444, 2005 15986235
244 Hovind P, Tarnow L, Rossing K, Rossing P, Eising S, Larsen N, Binder C, Parving HH: Decreasing incidence of severe diabetic microangiopathy in type 1 diabetes. Diabetes Care 26:1258–1264, 2003 12663607
245 The effect of intensive treatment of diabetes on the development and progression of long-term complications in insulin-dependent diabetes mellitus. The Diabetes Control and Complications Trial Research Group. N Engl J Med 329:977–986, 1993 8366922
246 Larson TS, Santanello N, Shahinfar S, O’Brien PC, Palumbo PJ, Melton LJ, 3rd, Leibson CL: Trends in persistent proteinuria in adult-onset diabetes: a population-based study. Diabetes Care 23:51–56, 2000 10857968
247 Pavkov ME, Knowler WC, Bennett PH, Looker HC, Krakoff J, Nelson RG: Increasing incidence of proteinuria and declining incidence of end-stage renal disease in diabetic Pima Indians. Kidney Int 70:1840–1846, 2006 17003816
248 Adler AI, Stevens RJ, Manley SE, Bilous RW, Cull CA, Holman RR; UKPDS Group: Development and progression of nephropathy in type 2 diabetes: the United Kingdom Prospective Diabetes Study (UKPDS 64). Kidney Int 63:225–232, 2003 12472787
249 Bilous R: Microvascular disease: what does the UKPDS tell us about diabetic nephropathy? Diabet Med 25(Suppl 2):25–29, 2008 18717975
250 Kussman MJ, Goldstein HH, Gleason RE: The clinical course of diabetic nephropathy. JAMA 236:1861–1863, 1976 989537
251 Rossing P, Hommel E, Smidt UM, Parving HH: Impact of arterial blood pressure and albuminuria on the progression of diabetic nephropathy in IDDM patients. Diabetes 42:715–719, 1993 8482428
252 Roy MS, Affouf M, Roy A: Six-year incidence of proteinuria in type 1 diabetic African Americans. Diabetes Care 30:1807–1812, 2007 17475942
253 Roy MS, Affouf M: Six-year progression of retinopathy and associated risk factors in African American patients with type 1 diabetes mellitus: the New Jersey 725. Arch Ophthalmol 124:1297–1306, 2006 16966625
254 Araki S, Haneda M, Sugimoto T, Isono M, Isshiki K, Kashiwagi A, Koya D: Factors associated with frequent remission of microalbuminuria in patients with type 2 diabetes. Diabetes 54:2983–2987, 2005 16186402
255 Gaede P, Tarnow L, Vedel P, Parving HH, Pedersen O: Remission to normoalbuminuria during multifactorial treatment preserves kidney function in patients with type 2 diabetes and microalbuminuria. Nephrol Dial Transplant 19:2784–2788, 2004 15328385
256 Pavkov ME, Knowler WC, Hanson RL, Bennett PH, Nelson RG: Predictive power of sequential measures of albuminuria for progression to ESRD or death in Pima Indians with type 2 diabetes. Am J Kidney Dis 51:759–766, 2008 18436086
257 Vupputuri S, Nichols GA, Lau H, Joski P, Thorp ML: Risk of progression of nephropathy in a population-based sample with type 2 diabetes. Diabetes Res Clin Pract 91:246–252, 2011 21156326
258 Xu J, Lee ET, Devereux RB, Umans JG, Bella JN, Shara NM, Yeh J, Fabsitz RR, Howard BV: A longitudinal study of risk factors for incident albuminuria in diabetic American Indians: the Strong Heart Study. Am J Kidney Dis 51:415–424, 2008 18295057
259 Xu J, Knowler WC, Devereux RB, Yeh J, Umans JG, Begum M, Fabsitz RR, Lee ET: Albuminuria within the “normal” range and risk of cardiovascular disease and death in American Indians: the Strong Heart Study. Am J Kidney Dis 49:208−216, 2007 17261423
260 Gerstein HC, Mann JF, Yi Q, Zinman B, Dinneen SF, Hoogwerf B, Halle JP, Young J, Rashkow A, Joyce C, Nawaz S, Yusuf S; HOPE Study Investigators: Albuminuria and risk of cardiovascular events, death, and heart failure in diabetic and nondiabetic individuals. JAMA 286:421–426, 2001 11466120
261 Yuyun MF, Adler AI, Wareham NJ: What is the evidence that microalbuminuria is a predictor of cardiovascular disease events? Curr Opin Nephrol Hypertens 14:271–276, 2005 15821422
262 Hillege HL, Fidler V, Diercks GF, van Gilst WH, de Zeeuw D, van Veldhuisen DJ, Gans RO, Janssen WM, Grobbee DE, de Jong PE; Prevention of Renal and Vascular End Stage Disease (PREVEND) Study Group: Urinary albumin excretion predicts cardiovascular and noncardiovascular mortality in general population. Circulation 106:1777–1782, 2002 12356629
263 Astor BC, Hallan SI, Miller ER, 3rd, Yeung E, Coresh J: Glomerular filtration rate, albuminuria, and risk of cardiovascular and all-cause mortality in the US population. Am J Epidemiol 167:1226–1234, 2008 18385206
264 Borch-Johnsen K, Andersen PK, Deckert T: The effect of proteinuria on relative mortality in type 1 (insulin-dependent) diabetes mellitus. Diabetologia 28:590–596, 1985 4054448
265 Nelson RG, Pettitt DJ, Carraher MJ, Baird HR, Knowler WC: Effect of proteinuria on mortality in NIDDM. Diabetes 37:1499–1504, 1988 3181642
266 Jensen T, Borch-Johnsen K, Kofoed-Enevoldsen A, Deckert T: Coronary heart disease in young type 1 (insulin-dependent) diabetic patients with and without diabetic nephropathy: incidence and risk factors. Diabetologia 30:144–148, 1987 3582820
267 Jarrett RJ: The epidemiology of coronary heart disease and related factors in the context of diabetes mellitus and impaired glucose tolerance. In Diabetes and Heart Disease. Jarrett RJ, Ed. Amsterdam, Elsevier, 1984, p. 1–23
268 Pavkov ME, Bennett PH, Sievers ML, Krakoff J, Williams DE, Knowler WC, Nelson RG: Predominant effect of kidney disease on mortality in Pima Indians with or without type 2 diabetes. Kidney Int 68:1267–1274, 2005 16105060
269 Orchard TJ, Secrest AM, Miller RG, Costacou T: In the absence of renal disease, 20 year mortality risk in type 1 diabetes is comparable to that of the general population: a report from the Pittsburgh Epidemiology of Diabetes Complications Study. Diabetologia 53:2312–2319, 2010 20665208
270 Arun CS, Stoddart J, Mackin P, Macleod JM, New JP, Marshall SM: Significance of microalbuminuria in long-duration type 1 diabetes. Diabetes Care 26:2144–2149, 2003 12832327
271 Allen KV, Walker JD: Microalbuminuria and mortality in long-duration type 1 diabetes. Diabetes Care 26:2389–2391, 2003 12882867
272 Rosolowsky ET, Skupien J, Smiles AM, Niewczas M, Roshan B, Stanton R, Eckfeldt JH, Warram JH, Krolewski AS: Risk for ESRD in type 1 diabetes remains high despite renoprotection. J Am Soc Nephrol 22:545–553, 2011 21355053
273 Nelson RG: Is treatment of nephropathy in type 1 diabetes efficacious but ineffective? J Am Soc Nephrol 22:402–404, 2011 21355059
274 Perrone RD, Madias NE, Levey AS: Serum creatinine as an index of renal function: new insights into old concepts. Clin Chem 38:1933–1953, 1992 1394976
275 Jarrett RJ, Viberti GC, Argyropoulos A, Hill RD, Mahmud U, Murrells TJ: Microalbuminuria predicts mortality in non-insulin-dependent diabetes. Diabet Med 1:17–19, 1984 6242771
276 Schmitz A, Vaeth M: Microalbuminuria: a major risk factor in non-insulin-dependent diabetes. A 10-year follow-up study of 503 patients. Diabet Med 5:126–134, 1988 2964977
277 Mattock MB, Morrish NJ, Viberti GC, Keen H, Fitzgerald AP, Jackson G: Prospective study of microalbuminuria as predictor of mortality in NIDDM. Diabetes 41:736–741, 1992 1587400
278 Niel A, Hawkins M, Potok M, Thorogood M, Cohen D, Mann J: A prospective population-based study of microalbuminuria as a predictor of mortality in NIDDM. Diabetes Care 16:996–1003, 1993 8359108
279 Liu JE, Robbins DC, Palmieri V, Bella JN, Roman MJ, Fabsitz R, Howard BV, Welty TK, Lee ET, Devereux RB: Association of albuminuria with systolic and diastolic left ventricular dysfunction in type 2 diabetes: the Strong Heart Study. J Am Coll Cardiol 41:2022–2028, 2003 12798576
280 Shara NM, Wang H, Mete M, Al-Balha YR, Azalddin N, Lee ET, Franceschini N, Jolly SE, Howard BV, Umans JG: Estimated GFR and incident cardiovascular disease events in American Indians: the Strong Heart Study. Am J Kidney Dis 60:795–803, 2012 22841159
281 Naqvi SB, Collins AJ: Infectious complications in chronic kidney disease. Adv Chronic Kidney Dis 13:199–204, 2006 16815225
282 McDonald HI, Thomas SL, Millett ER, Nitsch D: CKD and the risk of acute, community-acquired infections among older people with diabetes mellitus: a retrospective cohort study using electronic health records. Am J Kidney Dis 66:60–68, 2015 25641062
283 Dalrymple LS, Katz R, Kestenbaum B, de Boer IH, Fried L, Sarnak MJ, Shlipak MG: The risk of infection-related hospitalization with decreased kidney function. Am J Kidney Dis 59:356–363, 2012 21906862
284 Burrows NR, Cho P, McKeever Bullard K, Narva AS, Eggers PW: Survival on dialysis among American Indians and Alaska Natives with diabetes in the United States, 1995–2010. Am J Public Health 104(Suppl 3):S490–S495, 2014 24754656
285 Ishikawa I: [Renal cell carcinoma in chronic hemodialysis patients. A 1998 questionnaire study.] [Article in Japanese] J Jpn Soc Dial Ther 33:181–188, 2000
286 Pfeffer MA, Burdmann EA, Chen CY, Cooper ME, de Zeeuw D, Eckardt KU, Feyzi JM, Ivanovich P, Kewalramani R, Levey AS, Lewis EF, McGill JB, McMurray JJ, Parfrey P, Parving HH, Remuzzi G, Singh AK, Solomon SD, Toto R; TREAT Investigators: A trial of darbepoetin alfa in type 2 diabetes and chronic kidney disease. N Engl J Med 361:2019–2032, 2009 19880844
287 Wong G, Hayen A, Chapman JR, Webster AC, Wang JJ, Mitchell P, Craig JC: Association of CKD and cancer risk in older people. J Am Soc Nephrol 20:1341–1350, 2009 19406977
288 Shebl FM, Warren JL, Eggers PW, Engels EA: Cancer risk among elderly persons with end-stage renal disease: a population-based case-control study. BMC Nephrol 13:65, 2012 22834953
289 Larsson SC, Wolk A: Diabetes mellitus and incidence of kidney cancer: a meta-analysis of cohort studies. Diabetologia 54:1013–1018, 2011 21274512
290 Habib SL, Rojna M: Diabetes and risk of cancer. ISRN Oncol 2013 Feb 7 [Epub] doi: 10.1155/2013/583786
291 Izzedine H, Perazella MA: Onconephrology: an appraisal of the cancer and chronic kidney disease links. Nephrol Dial Transplant 30:1979–1988, 2015 25648910
292 Berhane AM, Weil EJ, Knowler WC, Nelson RG, Hanson RL: Albuminuria and estimated glomerular filtration rate as predictors of diabetic end-stage renal disease and death. Clin J Am Soc Nephrol 6:2444–2451, 2011 21852671
293 Ninomiya T, Perkovic V, de Galan BE, Zoungas S, Pillai A, Jardine M, Patel A, Cass A, Neal B, Poulter N, Mogensen CE, Cooper M, Marre M, Williams B, Hamet P, Mancia G, Woodward M, MacMahon S, Chalmers J; ADVANCE Collaborative Group: Albuminuria and kidney function independently predict cardiovascular and renal outcomes in diabetes. J Am Soc Nephrol 20:1813–1821, 2009 19443635
294 Shara NM, Wang H, Valaitis E, Pehlivanova M, Carter EA, Resnick HE, Wang W, Umans JG, Lee ET, Howard BV, Devereux RB, Wilson PW: Comparison of estimated glomerular filtration rates and albuminuria in predicting risk of coronary heart disease in a population with high prevalence of diabetes mellitus and renal disease. Am J Cardiol 107:399–405, 2011 21257005
295 Rosenson RS, Fioretto P, Dodson PM: Does microvascular disease predict macrovascular events in type 2 diabetes? Atherosclerosis 218:13–18, 2011 21763654
296 Yokoyama H, Oishi M, Kawai K, Sone H; Japan Diabetes Clinical Data Management Study Group: Reduced GFR and microalbuminuria are independently associated with prevalent cardiovascular disease in type 2 diabetes: JDDM study 16. Diabet Med 25:1426–1432, 2008 19046241
297 Tong PC, Kong AP, So WY, Yang X, Ng MC, Ho CS, Ma RC, Ozaki R, Ng V, Chow CC, Lam CW, Chan JC, Cockram CS: Interactive effect of retinopathy and macroalbuminuria on all-cause mortality, cardiovascular and renal end points in Chinese patients with type 2 diabetes mellitus. Diabet Med 24:741–746, 2007 17403120
298 So WY, Kong AP, Ma RC, Ozaki R, Szeto CC, Chan NN, Ng V, Ho HS, Lam CW, Chow CC, Cockram CS, Chan JC, Tong PC: Glomerular filtration rate, cardiorenal end points and all-cause mortality in type 2 diabetic patients. Diabetes Care 29:2046–2052, 2006 16936151
299 Gimeno-Orna JA, Lou-Arnal LM, Boned-Juliani B, Molinero-Herguedas E: Mild renal insufficiency as a cardiovascular risk factor in non-proteinuric type II diabetes. Diabetes Res Clin Pract 64:191–199, 2004 15126007
300 Yang X, Ma RC, So WY, Ko GT, Kong AP, Lam CW, Ho CS, Cockram CS, Wong VC, Tong PC, Chan JC: Impacts of chronic kidney disease and albuminuria on associations between coronary heart disease and its traditional risk factors in type 2 diabetic patients—the Hong Kong diabetes registry. Cardiovasc Diabetol 6:37, 2007 18053157
301 Leelawattana R, Rattarasarn C, Lim A, Soonthornpun S, Setasuban W: Causes of death, incidence and risk factors of cardiovascular diseases in Thai type 2 diabetic patients: a 5 year follow-up study. Diabetes Res Clin Pract 60:183–189, 2003 12822563
302 Juutilainen A, Lehto S, Ronnemaa T, Pyorala K, Laakso M: Proteinuria and metabolic syndrome as predictors of cardiovascular death in non-diabetic and type 2 diabetic men and women. Diabetologia 49:56–65, 2006 16365726
303 Bruno G, Merletti F, Bargero G, Novelli G, Melis D, Soddu A, Perotto M, Pagano G, Cavallo-Perin P: Estimated glomerular filtration rate, albuminuria and mortality in type 2 diabetes: the Casale Monferrato study. Diabetologia 50:941–948, 2007 17333106
304 Casiglia E, Zanette G, Mazza A, Donadon V, Donada C, Pizziol A, Tikhonoff V, Palatini P, Pessina AC: Cardiovascular mortality in non-insulin-dependent diabetes mellitus. A controlled study among 683 diabetics and 683 age- and sex-matched normal subjects. Eur J Epidemiol 16:677–684, 2000 11078126
305 Valmadrid CT, Klein R, Mos SE, Klein BE: The risk of cardiovascular disease mortality associated with microalbuminuria and gross proteinuria in persons with older-onset diabetes mellitus. Arch Intern Med 160:1093–1100, 2000 10789601
306 Yang X, So WY, Kong AP, Ho CS, Lam CW, Stevens RJ, Lyu RR, Yin DD, Cockram CS, Tong PC, Wong V, Chan JC: Development and validation of stroke risk equation for Hong Kong Chinese patients with type 2 diabetes: the Hong Kong Diabetes Registry. Diabetes Care 30:65–70, 2007 17192335
307 Davis TM, Millns H, Stratton IM, Holman RR, Turner RC: Risk factors for stroke in type 2 diabetes mellitus: United Kingdom Prospective Diabetes Study (UKPDS) 29. Arch Intern Med 159:1097–1103, 1999 10335687
308 Knobler H, Zornitzki T, Vered S, Oettinger M, Levy R, Caspi A, Faraggi D, Livschitz S: Reduced glomerular filtration rate in asymptomatic diabetic patients: predictor of increased risk for cardiac events independent of albuminuria. J Am Coll Cardiol 44:2142–2148, 2004 15582311
309 Fox CS, Matsushita K, Woodward M, Bilo HJ, Chalmers J, Heerspink HJ, Lee BJ, Perkins RM, Rossing P, Sairenchi T, Tonelli M, Vassalotti JA, Yamagishi K, Coresh J, de Jong PE, Wen CP, Nelson RG; Chronic Kidney Disease Prognosis Consortium: Associations of kidney disease measures with mortality and end-stage renal disease in individuals with and without diabetes: a meta-analysis. Lancet 380:1662–1673, 2012 23013602
310 Muntner P, Coresh J, Powe NR, Klag MJ: The contribution of increased diabetes prevalence and improved myocardial infarction and stroke survival to the increase in treated end-stage renal disease. J Am Soc Nephrol 14:1568–1577, 2003 12761257
311 Cowie CC, Port FK, Wolfe RA, Savage PJ, Moll PP, Hawthorne VM: Disparities in incidence of diabetic end-stage renal disease according to race and type of diabetes. N Engl J Med 321:1074–1079, 1989 2797067
312 Nelson RG, Newman JM, Knowler WC, Sievers ML, Kunzelman CL, Pettitt DJ, Moffett CD, Teutsch SM, Bennett PH: Incidence of end-stage renal disease in type 2 (non-insulin dependent) diabetes mellitus in Pima Indians. Diabetologia 31:730–736, 1988 3240833
313 Rostand SG, Kirk KA, Rutsky EA, Pate BA: Racial differences in the incidence of treatment for end-stage renal disease. N Engl J Med 306:1276–1279, 1982 7040967
314 Lopes AA, Port FK, James SA, Agodoa L: The excess risk of treated end-stage renal disease in blacks in the United States. J Am Soc Nephrol 3:1961–1971, 1993 8338929
315 Stephens GW, Gillaspy JA, Clyne D, Mejia A, Pollak VE: Racial differences in the incidence of end-stage renal disease in types I and II diabetes mellitus. Am J Kidney Dis 15:562–567, 1990 2368696
316 Pugh JA, Stern MP, Haffner SM, Eifler CW, Zapata M: Excess incidence of treatment of end-stage renal disease in Mexican Americans. Am J Epidemiol 127:135–144, 1988 3276155
317 Burden AC, McNally PG, Feehally J, Walls J: Increased incidence of end-stage renal failure secondary to diabetes mellitus in Asian ethnic groups in the United Kingdom. Diabet Med 9:641–645, 1992 1511571
318 Newman JM, Marfin AA, Eggers PW, Helgerson SD: End state renal disease among Native Americans, 1983–86. Am J Public Health 80:318–319, 1990 2305914
319 Pavkov ME, Bennett PH, Knowler WC, Krakoff J, Sievers ML, Nelson RG: Effect of youth-onset type 2 diabetes on incidence of end-stage renal disease and mortality in young and middle-aged Pima Indians. JAMA 296:421–426, 2006 16868300
320 Pavkov ME, Hanson RL, Knowler WC, Sievers ML, Bennett PH, Nelson RG: Effect of intrauterine diabetes exposure on the incidence of end-stage renal disease in young adults with type 2 diabetes. Diabetes Care 33:2396–2398, 2010 20693350
321 McMillan MA, Briggs JD, Junor BJ: Outcome of renal replacement treatment in patients with diabetes mellitus. BMJ 301:540–544, 1990 2207427
322 Hirschl MM, Heinz G, Sunder-Plassmann G, Derfler K: Renal replacement therapy in type 2 diabetic patients: 10 years’ experience. Am J Kidney Dis 20:564–568, 1992 1462983
323 Rischen-Vos J, van der Woude FJ, Tegzess AM, Zwinderman AH, Gooszen HC, van den Akker PJ, van Es LA: Increased morbidity and mortality in patients with diabetes mellitus after kidney transplantation as compared with non-diabetic patients. Nephrol Dial Transplant 7:433–437, 1992 1321380
324 Koch M, Thomas B, Tschope W, Ritz E: Survival and predictors of death in dialysed diabetic patients. Diabetologia 36:1113–1117, 1993 8243864
325 Cowie CC, Port FK, Rust KF, Harris MI: Differences in survival between black and white patients with diabetic end-stage renal disease. Diabetes Care 17:681–687, 1994 7924777
326 Yan G, Norris KC, Yu AJ, Ma JZ, Greene T, Yu W, Cheung AK: The relationship of age, race, and ethnicity with survival in dialysis patients. Clin J Am Soc Nephrol 8:953–961, 2013 23539227
327 Murthy BV, Molony DA, Stack AG: Survival advantage of Hispanic patients initiating dialysis in the United States is modified by race. J Am Soc Nephrol 16:782–790, 2005 15677309
328 Nelson RG, Hanson RL, Pettitt DJ, Knowler WC, Bennett PH: Survival during renal replacement therapy for diabetic end-stage renal disease in Pima Indians. Diabetes Care 19:1333–1337, 1996 8941459
329 Wolfe RA, Ashby VB, Milford EL, Ojo AO, Ettenger RE, Agodoa LY, Held PJ, Port FK: Comparison of mortality in all patients on dialysis, patients on dialysis awaiting transplantation, and recipients of a first cadaveric transplant. N Engl J Med 341:1725–1730, 1999 10580071
330 McFarlane PA: Should patients remain on intensive hemodialysis rather than choosing to receive a kidney transplant? Semin Dial 23:516–519, 2010 21039877
331 Port FK, Wolfe RA, Mauger EA, Berling DP, Jiang K: Comparison of survival probabilities for dialysis patients vs cadaveric renal transplant recipients. JAMA 270:1339–1343, 1993 8360969
332 Humphrey LL, Ballard DJ, Frohnert PP, Chu CP, O’Fallon WM, Palumbo PJ: Chronic renal failure in non-insulin-dependent diabetes mellitus. A population-based study in Rochester, Minnesota. Ann Intern Med 111:788–796, 1989 2817626
333 Hasslacher C, Ritz E, Wahl P, Michael C: Similar risks of nephropathy in patients with type I or type II diabetes mellitus. Nephrol Dial Transplant 4:859–863, 1989 2515489
334 Pugh JA, Medina R, Ramirez M: Comparison of the course to end-stage renal disease of type 1 (insulin-dependent) and type 2 (non-insulin-dependent) diabetic nephropathy. Diabetologia 36:1094–1098, 1993 8243860
335 Norris K, Nissenson AR: Race, gender, and socioeconomic disparities in CKD in the United States. J Am Soc Nephrol 19:1261–1270, 2008 18525000
336 Barbour SJ, Schachter M, Er L, Djurdjev O, Levin A: A systematic review of ethnic differences in the rate of renal progression in CKD patients. Nephrol Dial Transplant 25:2422–2430, 2010 20519230
337 Ward MM: Socioeconomic status and the incidence of ESRD. Am J Kidney Dis 51:563–572, 2008 18371532
338 Painter RC, Osmond C, Gluckman P, Hanson M, Phillips DI, Roseboom TJ: Transgenerational effects of prenatal exposure to the Dutch famine on neonatal adiposity and health in later life. BJOG 115:1243–1249, 2008 18715409
339 Klein R, Klein BE, Moss SE: Prevalence of microalbuminuria in older-onset diabetes. Diabetes Care 16:1325–1330, 1993 8269789
340 Coonrod BA, Ellis D, Becker DJ, Bunker CH, Kelsey SF, Lloyd CE, Drash AL, Kuller LH, Orchard TJ: Predictors of microalbuminuria in individuals with IDDM. Pittsburgh Epidemiology of Diabetes Complications Study. Diabetes Care 16:1376–1383, 1993 8269796
341 Hasslacher C, Stech W, Wahl P, Ritz E: Blood pressure and metabolic control as risk factors for nephropathy in type 1 (insulin-dependent) diabetes. Diabetologia 28:6–11, 1985 3979689
342 Nelson RG, Knowler WC, Pettitt DJ, Hanson RL, Bennett PH: Incidence and determinants of elevated urinary albumin excretion in Pima Indians with NIDDM. Diabetes Care 18:182–187, 1995 7729295
343 Cooper ME, Frauman A, O’Brien RC, Seeman E, Murray RM, Jerums G: Progression of proteinuria in type 1 and type 2 diabetes. Diabet Med 5:361–368, 1988 2968887
344 Fabre J, Balant LP, Dayer PG, Fox HM, Vernet AT: The kidney in maturity onset diabetes mellitus: a clinical study of 510 patients. Kidney Int 21:730–738, 1982 7109459
345 Niskanen L, Voutilainen R, Terasvirta M, Lehtinen J, Teppo AM, Groop L, Uusitupa M: A prospective study of clinical and metabolic associates of proteinuria in patients with type 2 diabetes mellitus. Diabet Med 10:543–549, 1993 8365091
346 Larkins RG, Dunlop ME: The link between hyperglycemia and diabetic nephropathy. Diabetologia 35:499–504, 1992 1612221
347 Mauer SM, Goetz FC, McHugh LE, Sutherland DE, Barbosa J, Najarian JS, Steffes MW: Long-term study of normal kidneys transplanted into patients with type I diabetes. Diabetes 38:516–523, 1989 2647558
348 Scott LJ, Warram JH, Hanna LS, Laffel LM, Ryan L, Krolewski AS: A nonlinear effect of hyperglycemia and current cigarette smoking are major determinants of the onset of microalbuminuria in type 1 diabetes. Diabetes 50:2842–2849, 2001 11723069
349 Romero P, Salvat M, Fernandez J, Baget M, Martinez I: Renal and retinal microangiopathy after 15 years of follow-up study in a sample of type 1 diabetes mellitus patients. J Diabetes Complications 21:93–100, 2007 17331857
350 Selvin E, Francis LM, Ballantyne CM, Hoogeveen RC, Coresh J, Brancati FL, Steffes MW: Nontraditional markers of glycemia: associations with microvascular conditions. Diabetes Care 34:960–967, 2011 21335368
351 Fioretto P, Bruseghin M, Berto I, Gallina P, Manzato E, Mussap M: Renal protection in diabetes: role of glycemic control. J Am Soc Nephrol 17(4 Suppl 2):S86–S89, 2006 16565255
352 Keane WF, Brenner BM, de Zeeuw D, Grunfeld JP, McGill J, Mitch WE, Ribeiro AB, Shahinfar S, Simpson RL, Snapinn SM, Toto R; RENAAL Study Investigators: The risk of developing end-stage renal disease in patients with type 2 diabetes and nephropathy: the RENAAL study. Kidney Int 63:1499–1507, 2003 12631367
353 Wiseman MJ, Saunders AJ, Keen H, Viberti G: Effect of blood glucose control on increased glomerular filtration rate and kidney size in insulin-dependent diabetes. N Engl J Med 312:617–621, 1985 3883162
354 Christiansen JS, Frandsen M, Parving HH: Effects of intravenous glucose infusion on renal function in normal man and in insulin-dependent diabetics. Diabetologia 21:368–373, 1981 7286497
355 Stackhouse S, Miller PL, Park SK, Meyer TW: Reversal of glomerular hyperfiltration and renal hypertrophy by blood glucose normalization in diabetic rats. Diabetes 39:989–995, 1990 2373266
356 Helal I, Fick-Brosnahan GM, Reed-Gitomer B, Schrier RW: Glomerular hyperfiltration: definitions, mechanisms and clinical implications. Nat Rev Nephrol 8:293–300, 2012 22349487
357 Cooper ME: Pathogenesis, prevention, and treatment of diabetic nephropathy. Lancet 352:213–219, 1998 9683226
358 Miller JA: Impact of hyperglycemia on the renin angiotensin system in early human type 1 diabetes mellitus. J Am Soc Nephrol 10:1778–1785, 1999 10446946
359 Satchell SC, Tooke JE: What is the mechanism of microalbuminuria in diabetes: a role for the glomerular endothelium? Diabetologia 51:714–725, 2008 18347777
360 Steffes MW, Sutherland DE, Goetz FC, Rich SS, Mauer SM: Studies of kidney and muscle biopsy specimens from identical twins discordant for type I diabetes mellitus. N Engl J Med 312:1282–1287, 1985 4039409
361 Fioretto P, Mauer M: Reversal of diabetic nephropathy: lessons from pancreas transplantation. J Nephrol 25:13–18, 2012 22241641
362 Mathiesen ER, Ronn B, Jensen T, Storm B, Deckert T: Relationship between blood pressure and urinary albumin excretion in development of microalbuminuria. Diabetes 39:245–249, 1990 2227133
363 Raal FJ, Kalk WJ, Taylor DR, Osler CE, Panz VR: The relationship between the development and progression of microalbuminuria and arterial blood pressure in type 1 (insulin-dependent) diabetes mellitus. Diabetes Res Clin Pract 16:221–227, 1992 1425143
364 Steinke JM: The natural progression of kidney injury in young type 1 diabetic patients. Curr Diab Rep 9:473–479, 2009 19954694
365 Schultz CJ, Neil HA, Dalton RN, Konopelska Bahu T, Dunger DB; Oxford Regional Prospective Study Group: Blood pressure does not rise before the onset of microalbuminuria in children followed from diagnosis of type 1 diabetes. Diabetes Care 24:555–560, 2001 11289484
366 Viberti GC, Keen H, Wiseman MJ: Raised arterial pressure in parents of proteinuric insulin dependent diabetics. Br Med J (Clin Res Ed) 295:515–517, 1987
367 Barzilay J, Warram JH, Bak M, Laffel LM, Canessa M, Krolewski AS: Predisposition to hypertension: risk factor for nephropathy and hypertension in IDDM. Kidney Int 41:723–730, 1992 1513093
368 Lurbe E, Redon J, Kesani A, Pascual JM, Tacons J, Alvarez V, Batlle D: Increase in nocturnal blood pressure and progression to microalbuminuria in type 1 diabetes. N Engl J Med 347:797–805, 2002 12226150
369 Nelson RG, Pettitt DJ, de Courten MP, Hanson RL, Knowler WC, Bennett PH: Parental hypertension and proteinuria in Pima Indians with NIDDM. Diabetologia 39:433–438, 1996 8777992
370 Nelson RG, Pettitt DJ, Baird HR, Charles MA, Liu QZ, Bennett PH, Knowler WC: Pre-diabetic blood pressure predicts urinary albumin excretion after the onset of type 2 (non-insulin-dependent) diabetes mellitus in Pima Indians. Diabetologia 36:998–1001, 1993 8243885
371 Canessa M, Adragna N, Solomon HS, Connolly TM, Tosteson DC: Increased sodium-lithium countertransport in red cells of patients with essential hypertension. N Engl J Med 302:772–776, 1980 7354809
372 Woods JW, Falk RJ, Pittman AW, Klemmer PJ, Watson BS, Namboodiri K: Increased red-cell sodium-lithium countertransport in normotensive sons of hypertensive parents. N Engl J Med 306:593–595, 1982 6949036
373 Clegg G, Morgan DB, Davidson C: The heterogeneity of essential hypertension. Relation between lithium efflux and sodium content of erythrocytes and a family history of hypertension. Lancet 2:891–894, 1982 6126750
374 Cooper R, LeGrady D, Nanas S, Trevisan M, Mansour M, Histand P, Ostrow D, Stamler J: Increased sodium-lithium countertransport in college students with elevated blood pressure. JAMA 249:1030–1034, 1983 6823057
375 Zerbini G, Gabellini D, Ruggieri D, Maestroni A: Increased sodium-lithium countertransport activity: a cellular dysfunction common to essential hypertension and diabetic nephropathy. J Am Soc Nephrol 15(Suppl 1):S81–S84, 2004 14684679
376 Mangili R, Bending JJ, Scott G, Li LK, Gupta A, Viberti G: Increased sodium-lithium countertransport activity in red cells of patients with insulin-dependent diabetes and nephropathy. N Engl J Med 318:146–150, 1988 3336402
377 Jones SL, Trevisan R, Tariq T, Semplicini A, Mattock M, Walker JD, Nosadini R, Viberti GC: Sodium-lithium countertransport in microalbuminuric insulin-dependent diabetic patients. Hypertension 15:570–575, 1990 2347619
378 Jensen JS, Mathiesen ER, Norgaard K, Hommel E, Borch-Johnsen K, Funder J, Brahm J, Parving HH, Deckert T: Increased blood pressure and erythrocyte sodium/lithium countertransport activity are not inherited in diabetic nephropathy. Diabetologia 33:619–624, 1990 2257999
379 Carr S, Mbanya JC, Thomas T, Keavey P, Taylor R, Alberti KG, Wilkinson R: Increase in glomerular filtration rate in patients with insulin-dependent diabetes and elevated erythrocyte sodium-lithium countertransport. N Engl J Med 322:500–505, 1990 2300121
380 Lopes de Faria JM, Silveira LA, Morgano M, Pavin EJ, Lopes de Faria JB: Erythrocyte sodium-lithium countertransport and proliferative diabetic retinopathy. Invest Ophthalmol Vis Sci 41:1482–1485, 2000 10798666
381 Elving LD, Wetzels JF, de Nobel E, Berden JH: Erythrocyte sodium-lithium countertransport is not different in type 1 (insulin-dependent) diabetic patients with and without diabetic nephropathy. Diabetologia 34:126–128, 1991 2065847
382 Gall MA, Rossing P, Jensen JS, Funder J, Parving HH: Red cell Na+/Li+ countertransport in non-insulin-dependent diabetics with diabetic nephropathy. Kidney Int 39:135–140, 1991 2002627
383 Giordano M, Castellino P, Solini A, Canessa ML, DeFronzo RA: Na+/Li+ and Na+/H+ countertransport activity in hypertensive non-insulin-dependent diabetic patients: role of insulin resistance and antihypertensive treatment. Metabolism 46:1316–1323, 1997 9361692
384 Fujita J, Tsuda K, Seno M, Obayashi H, Fukui I, Seino Y: Erythrocyte sodium-lithium countertransport activity as a marker of predisposition to hypertension and diabetic nephropathy in NIDDM. Diabetes Care 17:977–982, 1994 7988318
385 Herman WH, Prior DE, Yassine MD, Weder AB: Nephropathy in NIDDM is associated with cellular markers for hypertension. Diabetes Care 16:815–818, 1993 8388330
386 Volzke H, Gruska S, Vogelgesang D, Kerner W, Kraatz G, Rettig R: Intracellular calcium and sodium-lithium countertransport in type 2 diabetic patients with and without albuminuria. Endocr J 53:773–781, 2006 16983181
387 Van Norren K, Thien T, Berden JH, Elving LD, De Pont JJ: Relevance of erythrocyte Na+/Li+ countertransport measurement in essential hypertension, hyperlipidaemia and diabetic nephropathy: a critical review. Eur J Clin Invest 28:339–352, 1998 9650006
388 Diamond JR, Karnovsky MJ: Focal and segmental glomerulosclerosis: analogies to atherosclerosis. Kidney Int 33:917–924, 1988 3292816
389 Moorhead JF, El-Nahas M, Chan MK, Varghese Z: Lipid nephrotoxicity in chronic progressive glomerular and tubulo-inter-stitial disease. Lancet 2:1309–1311, 1982 6128601
390 Cases A, Coll E: Dyslipidemia and the progression of renal disease in chronic renal failure patients. Kidney Int Suppl 99:S87–S93, 2005
391 Marcovecchio ML, Dalton RN, Prevost AT, Acerini CL, Barrett TG, Cooper JD, Edge J, Neil A, Shield J, Widmer B, Todd JA, Dunger DB: Prevalence of abnormal lipid profiles and the relationship with the development of microalbuminuria in adolescents with type 1 diabetes. Diabetes Care 32:658–663, 2009 19171721
392 Ku E, Campese V: Is lipid management effective for all stages of CKD? Blood Purif 35:26–30, 2013
393 Jenkins AJ, Lyons TJ, Zheng D, Otvos JD, Lackland DT, McGee D, Garvey WT, Klein RL; DCCT/EDIC Research Group: Lipoproteins in the DCCT/EDIC cohort: associations with diabetic nephropathy. Kidney Int 64:817–828, 2003 12911531
394 Kwan BC, Kronenberg F, Beddhu S, Cheung AK: Lipoprotein metabolism and lipid management in chronic kidney disease. J Am Soc Nephrol 18:1246–1261, 2007 17360943
395 Krentz AJ: Lipoprotein abnormalities and their consequences for patients with type 2 diabetes. Diabetes Obes Metab 5(Suppl 1):S19–S27, 2003 14984018
396 Thomas MC, Rosengard-Barlund M, Mills V, Ronnback M, Thomas S, Forsblom C, Cooper ME, Taskinen MR, Viberti G, Groop PH: Serum lipids and the progression of nephropathy in type 1 diabetes. Diabetes Care 29:317–322, 2006 16443880
397 Thorn LM, Forsblom C, Fagerudd J, Thomas MC, Pettersson-Fernholm K, Saraheimo M, Waden J, Ronnback M, Rosengard-Barlund M, Bjorkesten CG, Taskinen MR, Groop PH FinnDiane Study Group: Metabolic syndrome in type 1 diabetes: association with diabetic nephropathy and glycemic control (the FinnDiane study). Diabetes Care 28:2019–2024, 2005 16043748
398 Kamanna VS: Low density lipoproteins and mitogenic signal transduction processes: role in the pathogenesis of renal disease. Histol Histopathol 17:497–505, 2002 11962755
399 Sibley SD, Hokanson JE, Steffes MW, Purnell JQ, Marcovina SM, Cleary PA, Brunzell JD: Increased small dense LDL and intermediate-density lipoprotein with albuminuria in type 1 diabetes. Diabetes Care 22:1165–1170, 1999 10388983
400 Retnakaran R, Cull CA, Thorne KI, Adler AI, Holman RR; UKPDS Study Group: Risk factors for renal dysfunction in type 2 diabetes: U.K. Prospective Diabetes Study 74. Diabetes 55:1832–1839, 2006 16731850
401 Tershakovec AM, Keane WF, Zhang Z, Lyle PA, Appel GB, McGill JB, Parving HH, Cooper ME, Shahinfar S, Brenner BM: Effect of LDL cholesterol and treatment with losartan on end-stage renal disease in the RENAAL study. Diabetes Care 31:445–447, 2008 18070995
402 Colhoun HM, Lee ET, Bennett PH, Lu M, Keen H, Wang SL, Stevens LK, Fuller JH: Risk factors for renal failure: the WHO Multinational Study of Vascular Disease in Diabetes. Diabetologia 44(Suppl 2):S46–S53, 2001 11587050
403 Rossi MC, Nicolucci A, Pellegrini F, Comaschi M, Ceriello A, Cucinotta D, Giorda C, Valentini U, Vespasiani G, De Cosmo S: Identifying patients with type 2 diabetes at high risk of microalbuminuria: results of the DEMAND (Developing Education on Microalbuminuria for Awareness of reNal and cardiovascular risk in Diabetes) Study. Nephrol Dial Transplant 23:1278–1284, 2008 18039647
404 Smulders YM, Rakic M, Stehouwer CD, Weijers RN, Slaats EH, Silberbusch J: Determinants of progression of microalbuminuria in patients with NIDDM. A prospective study. Diabetes Care 20:999–1005, 1997 9167114
405 Fagot-Campagna A, Nelson RG, Knowler WC, Pettitt DJ, Robbins DC, Go O, Welty TK, Lee ET, Howard BV: Plasma lipoproteins and the incidence of abnormal excretion of albumin in diabetic American Indians: the Strong Heart Study. Diabetologia 41:1002–1009, 1998 9754817
406 Cooper ME, Jandeleit-Dahm KA: Lipids and diabetic renal disease. Curr Diab Rep 5:445–448, 2005 16316596
407 Gyebi L, Soltani Z, Reisin E: Lipid nephrotoxicity: new concept for an old disease. Curr Hypertens Rep 14:177–181, 2012 22290079
408 Attia DM, Feron O, Goldschmeding R, Radermakers LH, Vaziri ND, Boer P, Balligand JL, Koomans HA, Joles JA: Hypercholesterolemia in rats induces podocyte stress and decreases renal cortical nitric oxide synthesis via an angiotensin II type 1 receptor-sensitive mechanism. J Am Soc Nephrol 15:949–957, 2004 15034097
409 Attia DM, Ni ZN, Boer P, Attia MA, Goldschmeding R, Koomans HA, Vaziri ND, Joles JA: Proteinuria is preceded by decreased nitric oxide synthesis and prevented by a NO donor in cholesterol-fed rats. Kidney Int 61:1776–1787, 2002 11967027
410 Chade AR, Zhu XY, Grande JP, Krier JD, Lerman A, Lerman LO: Simvastatin abates development of renal fibrosis in experimental renovascular disease. J Hypertens 26:1651–1660, 2008 18622245
411 Feron O, Dessy C, Moniotte S, Desager JP, Balligand JL: Hypercholesterolemia decreases nitric oxide production by promoting the interaction of caveolin and endothelial nitric oxide synthase. J Clin Invest 103:897–905, 1999 10079111
412 Romero JC, Reckelhoff JF: State-of-the-Art lecture. Role of angiotensin and oxidative stress in essential hypertension. Hypertension 34:943–949, 1999 10523389
413 Kopkan L, Khan MA, Lis A, Awayda MS, Majid DS: Cholesterol induces renal vasoconstriction and anti-natriuresis by inhibiting nitric oxide production in anesthetized rats. Am J Physiol Renal Physiol 297:F1606–F1613, 2009 19776170
414 Nosadini R, Tonolo G: Role of oxidized low density lipoproteins and free fatty acids in the pathogenesis of glomerulopathy and tubulointerstitial lesions in type 2 diabetes. Nutr Metab Cardiovasc Dis 21:79–85, 2011 21186102
415 Tang C, Kanter JE, Bornfeldt KE, Leboeuf RC, Oram JF: Diabetes reduces the cholesterol exporter ABCA1 in mouse macrophages and kidneys. J Lipid Res 51:1719–1728, 2010 19965614
416 Proctor G, Jiang T, Iwahashi M, Wang Z, Li J, Levi M: Regulation of renal fatty acid and cholesterol metabolism, inflammation, and fibrosis in Akita and OVE26 mice with type 1 diabetes. Diabetes 55:2502–2509, 2006 16936198
417 Merscher-Gomez S, Guzman J, Pedigo CE, Lehto M, Aguillon-Prada R, Mendez A, Lassenius MI, Forsblom C, Yoo T, Villarreal R, Maiguel D, Johnson K, Goldberg R, Nair V, Randolph A, Kretzler M, Nelson RG, Burke GW, 3rd, Groop PH, Fornoni A; FinnDiane Study Group: Cyclodextrin protects podocytes in diabetic kidney disease. Diabetes 62:3817–3827, 2013 23835338
418 Herman-Edelstein M, Scherzer P, Tobar A, Levi M, Gafter U: Altered renal lipid metabolism and renal lipid accumulation in human diabetic nephropathy. J Lipid Res 55:561–572, 2014 24371263
419 van Nielen M, Feskens EJ, Mensink M, Sluijs I, Molina E, Amiano P, Ardanaz E, Balkau B, Beulens JW, Boeing H, Clavel-Chapelon F, Fagherazzi G, Franks PW, Halkjaer J, Huerta JM, Katzke V, Key TJ, Khaw KT, Krogh V, Kuhn T, Menendez VV, Nilsson P, Overvad K, Palli D, Panico S, Rolandsson O, Romieu I, Sacerdote C, Sanchez MJ, Schulze MB, Spijkerman AM, Tjonneland A, Tumino R, van der A DL, Wurtz AM, Zamora-Ros R, Langenberg C, Sharp SJ, Forouhi NG, Riboli E, Wareham NJ; InterAct Consortium: Dietary protein intake and incidence of type 2 diabetes in Europe: the EPIC-InterAct Case-Cohort Study. Diabetes Care 37:1854–1862, 2014 24722499
420 Hoogeveen EK, Kostense PJ, Jager A, Heine RJ, Jakobs C, Bouter LM, Donker AJ, Stehouwer CD: Serum homocysteine level and protein intake are related to risk of microalbuminuria: the Hoorn Study. Kidney Int 54:203–209, 1998 9648080
421 Brenner BM, Meyer TW, Hostetter TH: Dietary protein intake and the progressive nature of kidney disease: the role of hemodynamically mediated glomerular injury in the pathogenesis of progressive glomerular sclerosis in aging, renal ablation, and intrinsic renal disease. N Engl J Med 307:652–659, 1982 7050706
422 Brenner BM: Hemodynamically mediated glomerular injury and the progressive nature of kidney disease. Kidney Int 23:647–655, 1983 6336299
423 Farr LE, Smadel JE: The effect of dietary protein on the course of nephrotoxic nephritis in rats. J Exp Med 70:615–627, 1939 19870934
424 Friend PS, Fernandes G, Good RA, Michael AF, Yunis EJ: Dietary restrictions early and late: effects on the nephropathy of the NZB x NZW mouse. Lab Invest 38:629–632, 1978 96299
425 Hostetter TH, Olson JL, Rennke HG, Venkatachalam MA, Brenner BM: Hyperfiltration in remnant nephrons: a potentially adverse response to renal ablation. Am J Physiol 241:F85–F93, 1981 7246778
426 Hostetter TH, Meyer TW, Rennke HG, Brenner BM: Chronic effects of dietary protein in the rat with intact and reduced renal mass. Kidney Int 30:509–517, 1986 3784291
427 Zatz R, Meyer TW, Rennke HG, Brenner BM: Predominance of hemodynamic rather than metabolic factors in the pathogenesis of diabetic glomerulopathy. Proc Natl Acad Sci U S A 82:5963–5967, 1985 3862110
428 Meek RL, LeBoeuf RC, Saha SA, Alpers CE, Hudkins KL, Cooney SK, Anderberg RJ, Tuttle KR: Glomerular cell death and inflammation with high-protein diet and diabetes. Nephrol Dial Transplant 28:1711–1720, 2013 23314315
429 Tuttle KR, Bruton JL, Perusek MC, Lancaster JL, Kopp DT, DeFronzo RA: Effect of strict glycemic control on renal hemodynamic response to amino acids and renal enlargement in insulin-dependent diabetes mellitus. N Engl J Med 324:1626–1632, 1991 2030719
430 Tuttle KR, Bruton JL: Effect of insulin therapy on renal hemodynamic response to amino acids and renal hypertrophy in non-insulin-dependent diabetes. Kidney Int 42:167–173, 1992 1635346
431 Uribarri J, Tuttle KR: Advanced glycation end products and nephrotoxicity of high-protein diets. Clin J Am Soc Nephrol 1:1293–1299, 2006 17699361
432 Banerjee T, Crews DC, Wesson DE, Tilea A, Saran R, Rios Burrows N, Williams DE, Powe NR; Centers for Disease Control and Prevention Chronic Kidney Disease Surveillance Team: Dietary acid load and chronic kidney disease among adults in the United States. BMC Nephrol 15:137, 2014 25151260
433 Shah SN, Abramowitz M, Hostetter TH, Melamed ML: Serum bicarbonate levels and the progression of kidney disease: a cohort study. Am J Kidney Dis 54:270–277, 2009 19394734
434 Whaley-Connell AT, Sowers JR, Stevens LA, McFarlane SI, Shlipak MG, Norris KC, Chen SC, Qiu Y, Wang C, Li S, Vassalotti JA, Collins AJ; Kidney Early Evaluation Program Investigators: CKD in the United States: Kidney Early Evaluation Program (KEEP) and National Health and Nutrition Examination Survey (NHANES) 1999–2004. Am J Kidney Dis 51(4 Suppl 2):S13–S20, 2008 18359403
435 Rudberg S, Stattin EL, Dahlquist G: Familial and perinatal risk factors for micro-and macroalbuminuria in young IDDM patients. Diabetes 47:1121–1126, 1998 9648837
436 Chase HP, Garg SK, Marshall G, Berg CL, Harris S, Jackson WE, Hamman RE: Cigarette smoking increases the risk of albuminuria among subjects with type 1 diabetes. JAMA 265:614–617, 1991 1987411
437 Muhlhauser I, Sawicki P, Berger M: Cigarette-smoking as a risk factor for macroproteinuria and proliferative retinopathy in type 1 (insulin-dependent) diabetes. Diabetologia 29:500–502, 1986 3758532
438 Hovind P, Rossing P, Tarnow L, Parving HH: Smoking and progression of diabetic nephropathy in type 1 diabetes. Diabetes Care 26:911–916, 2003 12610058
439 Muhlhauser I, Bender R, Bott U, Jorgens V, Grusser M, Wagener W, Overmann H, Berger M: Cigarette smoking and progression of retinopathy and nephropathy in type 1 diabetes. Diabet Med 13:536–543, 1996 8799657
440 Biesenbach G, Janko O, Zazgornik J: Similar rate of progression in the predialysis phase in type I and type II diabetes mellitus. Nephrol Dial Transplant 9:1097–1102, 1994 7800207
441 Sawicki PT, Didjurgeit U, Muhlhauser I, Bender R, Heinemann L, Berger M: Smoking is associated with progression of diabetic nephropathy. Diabetes Care 17:126–131, 1994 8137682
442 Hsu CC, Hwang SJ, Tai TY, Chen T, Huang MC, Shin SJ, Wen CP, Shih YT, Yang HJ, Chang CT, Chang CJ, Loh CH, Fuh MT, Li YS, Chang HY: Cigarette smoking and proteinuria in Taiwanese men with type 2 diabetes mellitus. Diabet Med 27:295–302, 2010 20536492
443 Chuahirun T, Khanna A, Kimball K, Wesson DE: Cigarette smoking and increased urine albumin excretion are interrelated predictors of nephropathy progression in type 2 diabetes. Am J Kidney Dis 41:13–21, 2003 12500217
444 Gambaro G, Bax G, Fusaro M, Normanno M, Manani SM, Zanella M, Dangelo A, Fedele D, Favaro S: Cigarette smoking is a risk factor for nephropathy and its progression in type 2 diabetes mellitus. Diabetes Nutr Metab 14:337–342, 2001 11853366
445 Afghahi H, Cederholm J, Eliasson B, Zethelius B, Gudbjornsdottir S, Hadimeri H, Svensson MK: Risk factors for the development of albuminuria and renal impairment in type 2 diabetes—the Swedish National Diabetes Register (NDR). Nephrol Dial Transplant 26:1236–1243, 2011 20817668
446 Jaimes EA, Tian RX, Raij L: Nicotine: the link between cigarette smoking and the progression of renal injury? Am J Physiol Heart Circ Physiol 292:H76–H82, 2007 16920799
447 Obert DM, Hua P, Pilkerton ME, Feng W, Jaimes EA: Environmental tobacco smoke furthers progression of diabetic nephropathy. Am J Med Sci 341:126–130, 2011 20924282
448 Czekaj P, Palasz A, Lebda-Wyborny T, Nowaczyk-Dura G, Karczewska W, Florek E, Kaminski M: Morphological changes in lungs, placenta, liver and kidneys of pregnant rats exposed to cigarette smoke. Int Arch Occup Environ Health 75(Suppl):S27–S35, 2002 12397408
449 Huang MF, Lin WL, Ma YC: A study of reactive oxygen species in mainstream of cigarette. Indoor Air 15:135–140, 2005 15737156
450 Wilkes HC, Kelleher C, Meade TW: Smoking and plasma fibrinogen. Lancet 1:307–308, 1988
451 Paterson AM, Mancia G, FitzGerald GA: Proceedings of the symposium on smoking: a risk factor for cardiovascular disease. Am Heart J 115(Suppl 2):S240–S294, 1988
452 Deckert T, Feldt-Rasmussen B, Borch-Johnsen K, Jensen T, Kofoed-Enevoldsen A: Albuminuria reflects widespread vascular damage. The Steno hypothesis. Diabetologia 32:219–226, 1989 2668076
453 Ogden CL, Flegal KM, Carroll MD, Johnson CL: Prevalence and trends in overweight among US children and adolescents, 1999–2000. JAMA 288:1728–1732, 2002 12365956
454 Nelson RG, Pavkov ME, Hanson RL, Knowler WC: Changing course of diabetic nephropathy in the Pima Indians. Diabetes Res Clin Pract 82(Suppl 1):S10–S14, 2008 18842316
455 Pavkov ME, Hanson RL, Knowler WC, Bennett PH, Krakoff J, Nelson RG: Changing patterns of type 2 diabetes incidence among Pima Indians. Diabetes Care 30:1758–1763, 2007 17468358
456 Wang Y, Chen X, Song Y, Caballero B, Cheskin LJ: Association between obesity and kidney disease: a systematic review and meta-analysis. Kidney Int 73:19–33, 2008 17928825
457 Kambham N, Markowitz GS, Valeri AM, Lin J, D’Agati VD: Obesity-related glomerulopathy: an emerging epidemic. Kidney Int 59:1498–1509, 2001 11260414
458 Zoccali C, Mallamaci F: Adiponectin and leptin in chronic kidney disease: causal factors or mere risk markers? J Ren Nutr 21:87–91, 2011 21195927
459 Alejandre Alcazar MA, Boehler E, Amann K, Klaffenbach D, Hartner A, Allabauer I, Wagner L, von Horsten S, Plank C, Dotsch J: Persistent changes within the intrinsic kidney-associated NPY system and tubular function by litter size reduction. Nephrol Dial Transplant 26:2453–2465, 2011 21367848
460 Straub RH, Schaller T, Miller LE, von Horsten S, Jessop DS, Falk W, Scholmerich J: Neuropeptide Y cotrans-mission with norepinephrine in the sympathetic nerve-macrophage interplay. J Neurochem 75:2464–2471, 2000 11080198
461 Alejandre Alcazar MA, Boehler E, Rother E, Amann K, Vohlen C, von Horsten S, Plank C, Dotsch J: Early postnatal hyperalimentation impairs renal function via SOCS-3 mediated renal postreceptor leptin resistance. Endocrinology 153:1397–1410, 2012 22253420
462 Taylor GW, Borgnakke WS: Periodontal disease: associations with diabetes, glycemic control and complications. Oral Dis 14:191–203, 2008 18336370
463 Akar H, Akar GC, Carrero JJ, Stenvinkel P, Lindholm B: Systemic consequences of poor oral health in chronic kidney disease patients. Clin J Am Soc Nephrol 6:218–226, 2011 21115624
464 Xiong X, Buekens P, Vastardis S, Pridjian G: Periodontal disease and gestational diabetes mellitus. Am J Obstet Gynecol 195:1086–1089, 2006 16846573
465 Kshirsagar AV, Craig RG, Moss KL, Beck JD, Offenbacher S, Kotanko P, Klemmer PJ, Yoshino M, Levin NW, Yip JK, Almas K, Lupovici EM, Usvyat LA, Falk RJ: Periodontal disease adversely affects the survival of patients with end-stage renal disease. Kidney Int 75:746–751, 2009 19165177
466 Shultis WA, Weil EJ, Looker HC, Curtis JM, Shlossman M, Genco RJ, Knowler WC, Nelson RG: Effect of periodontitis on overt nephropathy and end-stage renal disease in type 2 diabetes. Diabetes Care 30:306–311, 2007 17259499
467 Fisher MA, Taylor GW, West BT, McCarthy ET: Bidirectional relationship between chronic kidney disease and periodontal disease: structural equation modeling. Kidney Int 79:347–355, 2011 20927035
468 Sanz M, D’Aiuto F, Deanfield J, Fernandez-Aviles F: European workshop in periodontal health and cardiovascular disease—scientific evidence on the association between periodontal and cardiovascular diseases: a review of the literature. Eur Heart J 12(Suppl B):B3–B12, 2010
469 Tonetti MS, D’Aiuto F, Nibali L, Donald A, Storry C, Parkar M, Suvan J, Hingorani AD, Vallance P, Deanfield J: Treatment of periodontitis and endothelial function. N Engl J Med 356:911–920, 2007 17329698
470 Agodoa LY, Francis ME, Eggers PW: Association of analgesic use with prevalence of albuminuria and reduced GFR in US adults. Am J Kidney Dis 51:573–583, 2008 18371533
471 Harirforoosh S, Jamali F: Renal adverse effects of nonsteroidal anti-inflammatory drugs. Expert Opin Drug Saf 8:669–681, 2009 19832117
472 Evans M, Fored CM, Bellocco R, Fitzmaurice G, Fryzek JP, McLaughlin JK, Nyren O, Elinder CG: Acetaminophen, aspirin and progression of advanced chronic kidney disease. Nephrol Dial Transplant 24:1908–1918, 2009 19155536
473 Musu M, Finco G, Antonucci R, Polati E, Sanna D, Evangelista M, Ribuffo D, Schweiger V, Fanos V: Acute nephrotoxicity of NSAID from the foetus to the adult. Eur Rev Med Pharmacol Sci 15:1461–1472, 2011 22288307
474 Adams DH, Michael J, Bacon PA, Howie AJ, McConkey B, Abu D: Non-steroidal anti-inflammatory drugs and renal failure. Lancet 1:57–60, 1986 2867313
475 Perneger TV, Whelton PK, Klag MJ: Risk of kidney failure associated with the use of acetaminophen, aspirin, and nonsteroidal antiinflammatory drugs. N Engl J Med 331:1675–1679, 1994 7969358
476 Clive DM, Stoff JS: Renal syndromes associated with nonsteroidal antiinflammatory drugs. N Engl J Med 310:563–572, 1984 6363936
477 Brater DC: Clinical aspects of renal prostaglandins and NSAID therapy. Semin Arthritis Rheum 17(3 Suppl 2):17–22, 1988 3334106
478 Stillman MT, Schlesinger PA: Nonsteroidal anti-inflammatory drug nephrotoxicity. Should we be concerned? Arch Intern Med 150:268–270, 1990 2405799
479 Patel NS, Cuzzocrea S, Collino M, Chaterjee PK, Mazzon E, Britti D, Yaqoob MM, Thiemermann C: The role of cycloxygenase-2 in the rodent kidney following ischaemia/reperfusion injury in vivo. Eur J Pharmacol 562:148–154, 2007 17343844
480 Cherney DZ, Miller JA, Scholey JW, Bradley TJ, Slorach C, Curtis JR, Dekker MG, Nasrallah R, Hebert RL, Sochett EB: The effect of cyclooxygenase-2 inhibition on renal hemodynamic function in humans with type 1 diabetes. Diabetes 57:688–695, 2008 18083781
481 Nath KA: Tubulointerstitial changes as a major determinant in the progression of renal damage. Am J Kidney Dis 20:1–17, 1992 1621674
482 Segal R, Lubart E, Leibovitz A, Iaina A, Caspi D: Renal effects of low dose aspirin in elderly patients. Isr Med Assoc J 8:679–682, 2006 17125112
483 Goldszer RC, Coodley EL, Rosner MI, Simons WM, Schwartz AB: Hyperkalemia associated with indomethacin. Arch Intern Med 141:802–804, 1981 7016059
484 Winkelmayer WC, Waikar SS, Mogun H, Solomon DH: Nonselective and cyclooxygenase-2-selective NSAIDs and acute kidney injury. Am J Med 121:1092–1098, 2008 19028206
485 Whelton A, Hamilton CW: Nonsteroidal anti-inflammatory drugs: effects on kidney function. J Clin Pharmacol 31:588–598, 1991 1894754
486 Curhan GC, Knight EL, Rosner B, Hankinson SE, Stampfer MJ: Lifetime nonnarcotic analgesic use and decline in renal function in women. Arch Intern Med 164:1519–1524, 2004 15277282
487 Rexrode KM, Buring JE, Glynn RJ, Stampfer MJ, Youngman LD, Gaziano JM: Analgesic use and renal function in men. JAMA 286:315–321, 2001 11466097
488 Wei L, MacDonald TM, Jennings C, Sheng X, Flynn RW, Murphy MJ: Estimated GFR reporting is associated with decreased nonsteroidal anti-inflammatory drug prescribing and increased renal function. Kidney Int 84:174–178, 2013 23486517
489 Radhakrishnan J, Perazella MA: Drug-induced glomerular disease: attention required! Clin J Am Soc Nephrol 10:1287–1290, 2015 25876771
490 Markowitz GS, Bomback AS, Perazella MA: Drug-induced glomerular disease: direct cellular injury. Clin J Am Soc Nephrol 10:1291–1299, 2015 25862776
491 McCullough PA, Adam A, Becker CR, Davidson C, Lameire N, Stacul F, Tumlin J; CIN Consensus Working Panel: Risk prediction of contrast-induced nephropathy. Am J Cardiol 98:27K–36K, 2006
492 Koopman RJ, Mainous AG, 3rd, Liszka HA, Colwell JA, Slate EH, Carnemolla MA, Everett CJ: Evidence of nephropathy and peripheral neuropathy in US adults with undiagnosed diabetes. Ann Fam Med 4:427–432, 2006 17003143
493 Sundkvist G, Lilja B: Autonomic neuropathy predicts deterioration in glomerular filtration rate in patients with IDDM. Diabetes Care 16:773–779, 1993 8495619
494 Lilja B, Nosslin B, Bergstrom B, Sundkvist G: Glomerular filtration rate, autonomic nerve function, and orthostatic blood pressure in patients with diabetes mellitus. Diabetes Res 2:179–181, 1985 4085171
495 Kim YK, Lee JE, Kim YG, Kim DJ, Oh HY, Yang CW, Kim KW, Huh W: Cardiac autonomic neuropathy as a predictor of deterioration of the renal function in normoalbuminuric, normotensive patients with type 2 diabetes mellitus. J Korean Med Sci 24(Suppl):S69–S74, 2009 19194565
496 Ewing DJ, Campbell IW, Clarke BF: The natural history of diabetic autonomic neuropathy. Q J Med 49:95–108, 1980 7433630
497 Bramham K, Rajasingham D: Pregnancy in diabetes and kidney disease. J Renal Care 38(Suppl 1):78–89, 2012
498 Biesenbach G, Stoger W, Zazgornik J: [Changes in renal protein excretion and kidney function in type I diabetics during and following pregnancy in relation to the stage of preexistent diabetic nephropathy]. [Article in German] Klin Wochenschr 65:1048–1053, 1987 3431031
499 Powe CE, Thadhani R: Diabetes and the kidney in pregnancy. Semin Nephrol 31:59–69, 2011 21266265
500 Diabetes Control and Complications Trial Research Group: Effect of pregnancy on microvascular complications in the Diabetes Control and Complications Trial. Diabetes Care 23:1084–1091, 2000 10937502
501 Gordon M, Landon MB, Samuels P, Hissrich S, Gabbe SG: Perinatal outcome and long-term follow-up associated with modern management of diabetic nephropathy. Obstet Gynecol 87:401–409, 1996 8598963
502 Rossing K, Jacobsen P, Hommel E, Mathiesen E, Svenningsen A, Rossing P, Parving HH: Pregnancy and progression of diabetic nephropathy. Diabetologia 45:36–41, 2002 11845221
503 Gordin D, Hiilesmaa V, Fagerudd J, Ronnback M, Forsblom C, Kaaja R, Teramo K, Groop PH; FinnDiane Study Group: Pre-eclampsia but not pregnancy-induced hypertension is a risk factor for diabetic nephropathy in type 1 diabetic women. Diabetologia 50:516–522, 2007 17216281
504 Rocco L, Gil FZ, da Fonseca Pletiskaitz TM, de Fatima Cavanal M, Gomes GN: Effect of sodium overload on renal function of offspring from diabetic mothers. Pediatr Nephrol 23:2053–2060, 2008 18574600
505 Nelson RG: Intrauterine determinants of diabetic kidney disease in disadvantaged populations. Kidney Int Suppl 83:S13–S16, 2003
506 Luyckx VA, Bertram JF, Brenner BM, Fall C, Hoy WE, Ozanne SE, Vikse BE: Effect of fetal and child health on kidney development and long-term risk of hypertension and kidney disease. Lancet 382:273–283, 2013 23727166
507 Ruta LA, Dickinson H, Thomas MC, Denton KM, Anderson WP, Kett MM: High-salt diet reveals the hypertensive and renal effects of reduced nephron endowment. Am J Physiol Renal Physiol 298:F1384–F1392, 2010 20335316
508 Pinheiro AR, Salvucci ID, Aguila MB, Mandarim-de-Lacerda CA: Protein restriction during gestation and/or lactation causes adverse transgenerational effects on biometry and glucose metabolism in F1 and F2 progenies of rats. Clin Sci (Lond) 114:381–392, 2008 17927565
509 Harrison M, Langley-Evans SC: Intergenerational programming of impaired nephrogenesis and hypertension in rats following maternal protein restriction during pregnancy. Br J Nutr 101:1020–1030, 2009 18778527
510 Reddy MA, Natarajan R: Epigenetics in diabetic kidney disease. J Am Soc Nephrol 22:2182–2185, 2011 22021712
511 Dabelea D, Hanson RL, Bennett PH, Roumain J, Knowler WC, Pettitt DJ: Increasing prevalence of type II diabetes in American Indian children. Diabetologia 41:904–910, 1998 9726592
512 Abi Khalil C, Travert F, Fetita S, Rouzet F, Porcher R, Riveline JP, Hadjadj S, Larger E, Roussel R, Vexiau P, Le Guludec D, Gautier JF, Marre M: Fetal exposure to maternal type 1 diabetes is associated with renal dysfunction at adult age. Diabetes 59:2631–2636, 2010 20622173
513 Abrahamson DR, Steenhard BM: Perinatal nephron programming is not so sweet in maternal diabetes. J Am Soc Nephrol 19:837–839, 2008 18385416
514 Tran S, Chen YW, Chenier I, Chan JS, Quaggin S, Hebert MJ, Ingelfinger JR, Zhang SL: Maternal diabetes modulates renal morphogenesis in offspring. J Am Soc Nephrol 19:943–952, 2008 18305124
515 White SL, Perkovic V, Cass A, Chang CL, Poulter NR, Spector T, Haysom L, Craig JC, Salmi IA, Chadban SJ, Huxley RR: Is low birth weight an antecedent of CKD in later life? A systematic review of observational studies. Am J Kidney Dis 54:248–261, 2009 19339091
516 Li S, Chen SC, Shlipak M, Bakris G, McCullough PA, Sowers J, Stevens L, Jurkovitz C, McFarlane S, Norris K, Vassalotti J, Klag MJ, Brown WW, Narva A, Calhoun D, Johnson B, Obialo C, Whaley-Connell A, Becker B, Collins AJ; Kidney Early Evaluation Program Investigators: Low birth weight is associated with chronic kidney disease only in men. Kidney Int 73:637–642, 2008 18094674
517 Hsu CW, Yamamoto KT, Henry RK, De Roos AJ, Flynn JT: Prenatal risk factors for childhood CKD. J Am Soc Nephrol 25:2105–2111, 2014 24744441
518 Seaquist ER, Goetz FC, Rich S, Barbosa J: Familial clustering of diabetic kidney disease. Evidence for genetic susceptibility to diabetic nephropathy. N Engl J Med 320:1161–1165, 1989 2710189
519 Borch-Johnsen K, Norgaard K, Hommel E, Mathiesen ER, Jensen JS, Deckert T, Parving HH: Is diabetic nephropathy an inherited complication? Kidney Int 41:719–722, 1992 1513092
520 Pettitt DJ, Saad MF, Bennett PH, Nelson RG, Knowler WC: Familial predisposition to renal disease in two generations of Pima Indians with type 2 (non-insulin-dependent) diabetes mellitus. Diabetologia 33:438–443, 1990 2401399
521 Hanson RL, Craig DW, Millis MP, Yeatts KA, Kobes S, Pearson JV, Lee AM, Knowler WC, Nelson RG, Wolford JK: Identification of PVT1 as a candidate gene for end-stage renal disease in type 2 diabetes using a pooling-based genome-wide single nucleotide polymorphism association study. Diabetes 56:975–983, 2007 17395743
522 Millis MP, Bowen D, Kingsley C, Watanabe RM, Wolford JK: Variants in the plasma-cytoma variant translocation gene (PVT1) are associated with end-stage renal disease attributed to type 1 diabetes. Diabetes 56:3027–3032, 2007 17881614
523 Pezzolesi MG, Poznik GD, Mychaleckyj JC, Paterson AD, Barati MT, Klein JB, Ng DP, Placha G, Canani LH, Bochenski J, Waggott D, Merchant ML, Krolewski B, Mirea L, Wanic K, Katavetin P, Kure M, Wolkow P, Dunn JS, Smiles A, Walker WH, Boright AP, Bull SB; DCCT/EDIC Research Group, Doria A, Rogus JJ, Rich SS, Warram JH, Krolewski AS: Genome-wide association scan for diabetic nephropathy susceptibility genes in type 1 diabetes. Diabetes 58:1403–1410, 2009 19252134
524 Writing Team for the Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Research Group: Sustained effect of intensive treatment of type 1 diabetes mellitus on development and progression of diabetic nephropathy: the Epidemiology of Diabetes Interventions and Complications (EDIC) study. JAMA 290:2159–2167, 2003 14570951
525 Pezzolesi MG, Poznik GD, Skupien J, Smiles AM, Mychaleckyj JC, Rich SS, Warram JH, Krolewski AS: An intergenic region on chromosome 13q33.3 is associated with the susceptibility to kidney disease in type 1 and 2 diabetes. Kidney Int 80:105–111, 2011 21412220
526 Craig DW, Millis MP, DiStefano JK: Genome-wide SNP genotyping study using pooled DNA to identify candidate markers mediating susceptibility to end-stage renal disease attributed to type 1 diabetes. Diabet Med 26:1090–1098, 2009 19929986
527 Shimazaki A, Kawamura Y, Kanazawa A, Sekine A, Saito S, Tsunoda T, Koya D, Babazono T, Tanaka Y, Matsuda M, Kawai K, Iiizumi T, Imanishi M, Shinosaki T, Yanagimoto T, Ikeda M, Omachi S, Kashiwagi A, Kaku K, Iwamoto Y, Kawamori R, Kikkawa R, Nakajima M, Nakamura Y, Maeda S: Genetic variations in the gene encoding ELMO1 are associated with susceptibility to diabetic nephropathy. Diabetes 54:1171–1178, 2005 15793258
528 Leak TS, Perlegas PS, Smith SG, Keene KL, Hicks PJ, Langefeld CD, Mychaleckyj JC, Rich SS, Kirk JK, Freedman BI, Bowden DW, Sale MM: Variants in intron 13 of the ELMO1 gene are associated with diabetic nephropathy in African Americans. Ann Hum Genet 73:152–159, 2009 19183347
529 Knowler WC, Coresh J, Elston RC, Freedman BI, Iyengar SK, Kimmel PL, Olson JM, Plaetke R, Sedor JR, Seldin MF; Family Investigation of Nephropathy and Diabetes Research Group: The Family Investigation of Nephropathy and Diabetes (FIND): design and methods. J Diabetes Complications 19:1–9, 2005 15642484
530 Iyengar SK, Abboud HE, Goddard KA, Saad MF, Adler SG, Arar NH, Bowden DW, Duggirala R, Elston RC, Hanson RL, Ipp E, Kao WH, Kimmel PL, Klag MJ, Knowler WC, Meoni LA, Nelson RG, Nicholas SB, Pahl MV, Parekh RS, Quade SR, Rich SS, Rotter JI, Scavini M, Schelling JR, Sedor JR, Sehgal AR, Shah VO, Smith MW, Taylor KD, Winkler CA, Zager PG, Freedman BI; Family Investigation of Nephropathy and Diabetes Research Group: Genome-wide scans for diabetic nephropathy and albuminuria in multiethnic populations: the Family Investigation of Nephropathy and Diabetes (FIND). Diabetes 56:1577–1585, 2007 17363742
531 Schelling JR, Abboud HE, Nicholas SB, Pahl MV, Sedor JR, Adler SG, Arar NH, Bowden DW, Elston RC, Freedman BI, Goddard KA, Guo X, Hanson RL, Ipp E, Iyengar SK, Jun G, Kao WH, Kasinath BS, Kimmel PL, Klag MJ, Knowler WC, Nelson RG, Parekh RS, Quade SR, Rich SS, Saad MF, Scavini M, Smith MW, Taylor K, Winkler CA, Zager PG, Shah VO; Family Investigation of Nephropathy and Diabetes Research Group: Genome-wide scan for estimated glomerular filtration rate in multi-ethnic diabetic populations: the Family Investigation of Nephropathy and Diabetes (FIND). Diabetes 57:235–243, 2008 18003762
532 Mooyaart AL, Valk EJ, van Es LA, Bruijn JA, de Heer E, Freedman BI, Dekkers OM, Baelde HJ: Genetic associations in diabetic nephropathy: a meta-analysis. Diabetologia 54:544–553, 2011 21127830
533 Langefeld CD, Beck SR, Bowden DW, Rich SS, Wagenknecht LE, Freedman BI: Heritability of GFR and albuminuria in Caucasians with type 2 diabetes mellitus. Am J Kidney Dis 43:796–800, 2004 15112169
534 Reddy MA, Zhang E, Natarajan R: Epigenetic mechanisms in diabetic complications and metabolic memory. Diabetologia 58:443–455, 2015 25481708
535 Alvarez ML, DiStefano JK: The role of non-coding RNAs in diabetic nephropathy: potential applications as biomarkers for disease development and progression. Diabetes Res Clin Pract 99:1–11, 2013 23102915
536 Dwivedi RS, Herman JG, McCaffrey TA, Raj DS: Beyond genetics: epigenetic code in chronic kidney disease. Kidney Int 79:23–32, 2011 20881938
537 Blood glucose control and the evolution of diabetic retinopathy and albuminuria. A preliminary multicenter trial. The Kroc Collaborative Study Group. N Engl J Med 311:365–372, 1984 6377076
538 Bending JJ, Viberti GC, Watkins PJ, Keen H: Intermittent clinical proteinuria and renal function in diabetes: evolution and effect of glycaemic control. Br Med J (Clin Res Ed) 292:83–86, 1986
539 Feldt-Rasmussen B, Mathiesen E, Deckert T: Effect of two years of strict metabolic control on progression of incipient nephropathy in insulin-dependent diabetes. Lancet 2:1300–1304, 1986 2878175
540 Dahl-Jorgensen K, Bjoro T, Kierulf P, Sandvik L, Bangstad HJ, Hanssen KF: Long-term glycemic control and kidney function in insulin-dependent diabetes mellitus. Kidney Int 41:920–923, 1992 1513113
541 Reichard P, Nilsson BY, Rosenqvist U: The effect of long-term intensified insulin treatment on the development of microvascular complications of diabetes mellitus. N Engl J Med 329:304–309, 1993 8147960
542 DCCT/EDIC Research Group; de Boer IH, Sun W, Cleary PA, Lachin JM, Molitch ME, Steffes MW, Zinman B: Intensive diabetes therapy and glomerular filtration rate in type 1 diabetes. N Engl J Med 365:2366–2376, 2011 22077236
543 Nathan DM, Cleary PA, Backlund JY, Genuth SM, Lachin JM, Orchard TJ, Raskin P, Zinman B; Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications (DCCT/EDIC) Study Research Group: Intensive diabetes treatment and cardiovascular disease in patients with type 1 diabetes. N Engl J Med 353:2643–2653, 2005 16371630
544 Holman RR, Paul SK, Bethel MA, Matthews DR, Neil HA: 10-year follow-up of intensive glucose control in type 2 diabetes. N Engl J Med 359:1577–1589, 2008 18784090
545 Del Prato S: Megatrials in type 2 diabetes. From excitement to frustration? Diabetologia 52:1219–1226, 2009 19373446
546 Duckworth WC, Abraira C, Moritz TE, Davis SN, Emanuele N, Goldman S, Hayward R, Huang GD, Marks JB, Reaven PD, Reda DJ, Warren SR, Zieve FJ; Investigators of the VADT: The duration of diabetes affects the response to intensive glucose control in type 2 subjects: the VA Diabetes Trial. J Diabetes Complications 25:355–361, 2011 22055259
547 Boussageon R, Bejan-Angoulvant T, Saadatian-Elahi M, Lafont S, Bergeonneau C, Kassai B, Erpeldinger S, Wright JM, Gueyffier F, Cornu C: Effect of intensive glucose lowering treatment on all cause mortality, cardiovascular death, and microvascular events in type 2 diabetes: meta-analysis of randomised controlled trials. BMJ 343:d4169, 2011 21791495
548 Ohkubo Y, Kishikawa H, Araki E, Miyata T, Isami S, Motoyoshi S, Kojima Y, Furuyoshi N, Shichiri M: Intensive insulin therapy prevents the progression of diabetic microvascular complications in Japanese patients with non-insulin-dependent diabetes mellitus: a randomized prospective 6-year study. Diabetes Res Clin Pract 28:103–117, 1995 7587918
549 Intensive blood-glucose control with sulphonylureas or insulin compared with conventional treatment and risk of complications in patients with type 2 diabetes, UKPDS 33. UK Prospective Diabetes Study (UKPDS) Group. Lancet 352:837–853, 1998 9742976
550 Effect of intensive blood-glucose control with metformin on complications in overweight patients with type 2 diabetes (UKPDS 34). UK Prospective Diabetes Study (UKPDS) Group. Lancet 352:854–865, 1998 9742977
551 Action to Control Cardiovascular Risk in Diabetes Study Group; Gerstein HC, Miller ME, Byington RP, Goff DC Jr, Bigger JT, Buse JB, Cushman WC, Genuth S, Ismail-Beigi F, Grimm RH Jr, Probstfield JL, Simons-Morton DG, Friedewald WT: Effects of intensive glucose lowering in type 2 diabetes. N Engl J Med 358:2545–2559, 2008 18539917
552 ADVANCE Collaborative Group; Patel A, MacMahon S, Chalmers J, Neal B, Billot L, Woodward M, Marre M, Cooper M, Glasziou P, Grobbee D, Hamet P, Harrap S, Heller S, Liu L, Mancia G, Mogensen CE, Pan C, Poulter N, Rodgers A, Williams B, Bompoint S, de Galan BE, Joshi R, Travert F: Intensive blood glucose control and vascular outcomes in patients with type 2 diabetes. N Engl J Med 358:2560–2572, 2008 18539916
553 Duckworth W, Abraira C, Moritz T, Reda D, Emanuele N, Reaven PD, Zieve FJ, Marks J, Davis SN, Hayward R, Warren SR, Goldman S, McCarren M, Vitek ME, Henderson WG, Huang GD; VADT Investigators: Glucose control and vascular complications in veterans with type 2 diabetes. N Engl J Med 360:129–139, 2009 19092145
554 National Kidney Foundation: KDOQI Clinical Practice Guideline for Diabetes and CKD: 2012 update. Am J Kidney Dis 60:850–886, 2012 23067652
555 Gerich JE, Meyer C, Woerle HJ, Stumvoll M: Renal gluconeogenesis: its importance in human glucose homeostasis. Diabetes Care 24:382−391, 2001 11213896
556 Williams ME: Management of diabetes in dialysis patients. Curr Diab Rep 9:466–472, 2009 19954693
557 Ix JH: Hemoglobin A1c in hemodialysis patients: should one size fit all? Clin J Am Soc Nephrol 5:1539–1541, 2010 20671219
558 Morgan L, Marenah CB, Jeffcoate WJ, Morgan AG: Glycated proteins as indices of glycaemic control in diabetic patients with chronic renal failure. Diabet Med 13:514–519, 1996 8799653
559 Joy MS, Cefalu WT, Hogan SL, Nachman PH: Long-term glycemic control measurements in diabetic patients receiving hemodialysis. Am J Kidney Dis 39:297–307, 2002 11840370
560 Inaba M, Okuno S, Kumeda Y, Yamada S, Imanishi Y, Tabata T, Okamura M, Okada S, Yamakawa T, Ishimura E, Nishizawa Y; Osaka CKD Expert Research Group: Glycated albumin is a better glycemic indicator than glycated hemoglobin values in hemodialysis patients with diabetes: effect of anemia and erythropoietin injection. J Am Soc Nephrol 18:896–903, 2007 17267743
561 Riveline JP, Teynie J, Belmouaz S, Franc S, Dardari D, Bauwens M, Caudwell V, Ragot S, Bridoux F, Charpentier G, Marechaud R, Hadjadj S: Glycaemic control in type 2 diabetic patients on chronic haemodialysis: use of a continuous glucose monitoring system. Nephrol Dial Transplant 24:2866–2871, 2009 19389864
562 Freedman BI, Shihabi ZK, Andries L, Cardona CY, Peacock TP, Byers JR, Russell GB, Stratta RJ, Bleyer AJ: Relationship between assays of glycemia in diabetic subjects with advanced chronic kidney disease. Am J Nephrol 31:375–379, 2010 20299782
563 Ng JM, Cooke M, Bhandari S, Atkin SL, Kilpatrick ES: The effect of iron and erythropoietin treatment on the A1C of patients with diabetes and chronic kidney disease. Diabetes Care 33:2310–2313, 2010 20798337
564 Ramirez SP, McCullough KP, Thumma JR, Nelson RG, Morgenstern H, Gillespie BW, Inaba M, Jacobson SH, Vanholder R, Pisoni RL, Port FK, Robinson BM: Hemoglobin A(1c) levels and mortality in the diabetic hemodialysis population: findings from the Dialysis Outcomes and Practice Patterns Study (DOPPS). Diabetes Care 35:2527–2532, 2012 22912431
565 Shurraw S, Hemmelgarn B, Lin M, Majumdar SR, Klarenbach S, Manns B, Bello A, James M, Turin TC, Tonelli M; Alberta Kidney Disease Network: Association between glycemic control and adverse outcomes in people with diabetes mellitus and chronic kidney disease. Arch Intern Med 171:1920–1927, 2011 22123800
566 Sturm G, Lamina C, Zitt E, Lhotta K, Haider F, Neyer U, Kronenberg F: Association of HbA1c values with mortality and cardiovascular events in diabetic dialysis patients. The INVOR study and review of the literature. PLOS ONE 6:e20093, 2011 21625600
567 Balamuthusamy S, Srinivasan L, Verma M, Adigopula S, Jalandara N, Hathiwala S, Smith E: Renin angiotensin system blockade and cardiovascular outcomes in patients with chronic kidney disease and proteinuria: a metaanalysis. Am Heart J 155:791–805, 2008 18440325
568 ACE Inhibitors in Diabetic Nephropathy Trialist Group: Should all patients with type 1 diabetes mellitus and microalbuminuria receive angiotensin-converting enzyme inhibitors? A meta-analysis of individual patient data. Ann Intern Med 134:370–379, 2001 11242497
569 Lemley KV: When to initiate ACEI/ARB therapy in patients with type 1 and 2 diabetes. Pediatr Nephrol 25:2021–2034, 2010 20352458
570 Lewis EJ, Hunsicker LG, Bain RP, Rohde RD: The effect of angiotensin-converting-enzyme inhibition on diabetic nephropathy. The Collaborative Study Group. N Engl J Med 329:1456–1462, 1993 8413456
571 Mauer M, Zinman B, Gardiner R, Suissa S, Sinaiko A, Strand T, Drummond K, Donnelly S, Goodyer P, Gubler MC, Klein R: Renal and retinal effects of enalapril and losartan in type 1 diabetes. N Engl J Med 361:40–51, 2009 19571282
572 Randomised placebo-controlled trial of lisinopril in normotensive patients with insulin-dependent diabetes and normoalbuminuria or microalbuminuria. The EUCLID Study Group. Lancet 349:1787–1792, 1997 9269212
573 Effects of ramipril on cardiovascular and microvascular outcomes in people with diabetes mellitus: results of the HOPE study and MICRO-HOPE substudy. Heart Outcomes Prevention Evaluation Study Investigators. Lancet 355:253–259, 2000 10675071
574 Ruggenenti P, Fassi A, Ilieva AP, Bruno S, Iliev IP, Brusegan V, Rubis N, Gherardi G, Arnoldi F, Ganeva M, Ene-Iordache B, Gaspari F, Perna A, Bossi A, Trevisan R, Dodesini AR, Remuzzi G; Bergamo Nephrologic Diabetes Complications Trial (BENEDICT) Investigators: Preventing microalbuminuria in type 2 diabetes. N Engl J Med 351:1941–1951, 2004 15516697
575 Ravid M, Brosh D, Levi Z, Bar-Dayan Y, Ravid D, Rachmani R: Use of enalapril to attenuate decline in renal function in normotensive, normoalbuminuric patients with type 2 diabetes mellitus. A randomized, controlled trial. Ann Intern Med 128:982–988, 1998 9625684
576 Bilous R, Chaturvedi N, Sjolie AK, Fuller J, Klein R, Orchard T, Porta M, Parving HH: Effect of candesartan on microalbuminuria and albumin excretion rate in diabetes: three randomized trials. Ann Intern Med 151:11–20, 2009 19451554
577 Mann JF, Schmieder RE, Dyal L, McQueen MJ, Schumacher H, Pogue J, Wang X, Probstfield JL, Avezum A, Cardona-Munoz E, Dagenais GR, Diaz R, Fodor G, Maillon JM, Ryden L, Yu CM, Teo KK, Yusuf S; TRANSCEND (Telmisartan Randomised Assessment Study in ACE Intolerant Subjects with Cardiovascular Disease) Investigators: Effect of telmisartan on renal outcomes a randomized trial. Ann Intern Med 151:1–10, 2009 19451556
578 Haller H, Ito S, Izzo JL, Jr., Januszewicz A, Katayama S, Menne J, Mimran A, Rabelink TJ, Ritz E, Ruilope LM, Rump LC, Viberti G; ROADMAP Trial Investigators: Olmesartan for the delay or prevention of microalbuminuria in type 2 diabetes. N Engl J Med 364:907–917, 2011 21388309
579 Parving HH, Lehnert H, Brochner-Mortensen J, Gomis R, Andersen S, Arner P; Irbesartan in Patients With Type 2 Diabetes and Microalbuminuria Study Group: The effect of irbesartan on the development of diabetic nephropathy in patients with type 2 diabetes. N Engl J Med 345:870–878, 2001 11565519
580 Brenner BM, Cooper ME, de Zeeuw D, Keane WF, Mitch WE, Parving HH, Remuzzi G, Snapinn SM, Zhang Z, Shahinfar S; RENAAL Study Investigators: Effects of losartan on renal and cardiovascular outcomes in patients with type 2 diabetes and nephropathy. N Engl J Med 345:861–869, 2001 11565518
581 Lewis EJ, Hunsicker LG, Clarke WR, Berl T, Pohl MA, Lewis JB, Ritz E, Atkins RC, Rohde R, Raz I; Collaborative Study Group: Renoprotective effect of the angiotensin-receptor antagonist irbesartan in patients with nephropathy due to type 2 diabetes. N Engl J Med 345:851–860, 2001 11565517
582 ONTARGET Investigators; Yusuf D, Teo KK, Pogue J, Dyal L, Copland I, Schumacher H, Dagenais G, Sleight P, Anderson C: Telmisartan, ramipril, or both in patients at high risk for vascular events. N Engl J Med 358:1547–1559, 2008 18378520
583 Barnett AH, Bain SC, Bouter P, Karlberg B, Madsbad S, Jervell J, Mustonen J; Diabetics Exposed to Telmisartan and Enalapril Study Group: Angiotensin-receptor blockade versus converting-enzyme inhibition in type 2 diabetes and nephropathy. N Engl J Med 351:1952–1961, 2004 15516696
584 Vejakama P, Thakkinstian A, Lertrattananon D, Ingsathit A, Ngarmukos C, Attia J: Reno-protective effects of renin-angiotensin system blockade in type 2 diabetic patients: a systematic review and network meta-analysis. Diabetologia 55:566–578, 2012 22189484
585 Lv J, Perkovic V, Foote CV, Craig ME, Craig JC, Strippoli GF: Antihypertensive agents for preventing diabetic kidney disease. Cochrane Database Syst Rev 12:CD004136, 2012 23235603
586 Strippoli GF, Craig M, Deeks JJ, Schena FP, Craig JC: Effects of angiotensin converting enzyme inhibitors and angiotensin II receptor antagonists on mortality and renal outcomes in diabetic nephropathy: systematic review. BMJ 329:828, 2004 15459003
587 Mann JF, Anderson C, Gao P, Gerstein HC, Boehm M, Ryden L, Sleight P, Teo KK, Yusuf S; ONTARGET Investigators: Dual inhibition of the renin-angiotensin system in high-risk diabetes and risk for stroke and other outcomes: results of the ONTARGET trial. J Hypertens 31:414–421, 2013 23249829
588 Croom KF, Curran MP, Goa KL, Perry CM: Irbesartan: a review of its use in hypertension and in the management of diabetic nephropathy. Drugs 64:999–1028, 2004 15101793
589 Mogensen CE, Neldam S, Tikkanen I, Oren S, Viskoper R, Watts RW, Cooper ME: Randomised controlled trial of dual blockade of renin-angiotensin system in patients with hypertension, microalbuminuria, and non-insulin dependent diabetes: the candesartan and lisinopril microalbuminuria (CALM) study. BMJ 321:1440–1444, 2000 11110735
590 Bakris GL, Ruilope L, Locatelli F, Ptaszynska A, Pieske B, de Champlain J, Weber MA, Raz I: Treatment of microalbuminuria in hypertensive subjects with elevated cardiovascular risk: results of the IMPROVE trial. Kidney Int 72:879–885, 2007 17667984
591 Fried LF, Emanuele N, Zhang JH, Brophy M, Conner TA, Duckworth W, Leehey DJ, McCullough PA, O’Connor T, Palevsky PM, Reilly RF, Seliger SL, Warren SR, Watnick S, Peduzzi P, Guarino P; VA NEPHRON-D Investigators: Combined angiotensin inhibition for the treatment of diabetic nephropathy. N Engl J Med 369:1892–1903, 2013 24206457
592 Parving HH, Persson F, Lewis JB, Lewis EJ, Hollenberg NK; AVOID Study Investigators: Aliskiren combined with losartan in type 2 diabetes and nephropathy. N Engl J Med 358:2433–2446, 2008 18525041
593 Parving HH, Brenner BM, McMurray JJ, de Zeeuw D, Haffner SM, Solomon SD, Chaturvedi N, Persson F, Desai AS, Nicolaides M, Richard A, Xiang Z, Brunel P, Pfeffer MA; ALTITUDE Investigators: Cardiorenal end points in a trial of aliskiren for type 2 diabetes. N Engl J Med 367:2204–2213, 2012 23121378
594 Bangalore S, Kumar S, Lobach I, Messerli FH: Blood pressure targets in subjects with type 2 diabetes mellitus/impaired fasting glucose observations from traditional and bayesian random-effects meta-analyses of randomized trials. Circulation 123:2799–2810, 2011 21632497
595 Klahr S, Levey AS, Beck GJ, Caggiula AW, Hunsicker L, Kusek JW, Striker G: The effects of dietary protein restriction and blood-pressure control on the progression of chronic renal disease. Modification of Diet in Renal Disease Study Group. N Engl J Med 330:877–884, 1994 8114857
596 Walker WG, Hermann J, Anderson J: Racial differences in renal protective effect of enalapril vs hydrochlorothiazide in randomized doubly blinded trial in hypertensive NIDDM (Abstract). J Am Soc Nephrol 4:A310, 1993
597 McClellan WM, Warnock DG, Judd S, Muntner P, Kewalramani R, Cushman M, McClure LA, Newsome BB, Howard G: Albuminuria and racial disparities in the risk for ESRD. J Am Soc Nephrol 22:1721–1728, 2011 21868498
598 Murea M, Freedman BI: Essential hypertension and risk of nephropathy: a reappraisal. Curr Opin Nephrol Hypertens 19:235–241, 2010 20051853
599 Weir MR, Bakris GL, Weber MA, Dahlof B, Devereux RB, Kjeldsen SE, Pitt B, Wright JT, Kelly RY, Hua TA, Hester RA, Velazquez E, Jamerson KA: Renal outcomes in hypertensive black patients at high cardiovascular risk. Kidney Int 81:568–576, 2012 22189843
600 James PA, Oparil S, Carter BL, Cushman WC, Dennison-Himmelfarb C, Handler J, Lackland DT, LeFevre ML, MacKenzie TD, Ogedegbe O, Smith SC, Jr., Svetkey LP, Taler SJ, Townsend RR, Wright JT, Jr., Narva AS, Ortiz E: 2014 evidence-based guideline for the management of high blood pressure in adults: report from the panel members appointed to the Eighth Joint National Committee (JNC 8). JAMA 311:507–520, 2014 24352797
601 American Diabetes Association: Cardiovascular disease and risk management. Sec. 8. In “Standards of Medical Care in Diabetes—2015.” Diabetes Care 38(Suppl 1):S49–S57, 2015 25537708
602 Dasgupta K, Quinn RR, Zarnke KB, Rabi DM, Ravani P, Daskalopoulou SS, Rabkin SW, Trudeau L, Feldman RD, Cloutier L, Prebtani A, Herman RJ, Bacon SL, Gilbert RE, Ruzicka M, McKay DW, Campbell TS, Grover S, Honos G, Schiffrin EL, Bolli P, Wilson TW, Lindsay P, Hill MD, Coutts SB, Gubitz G, Gelfer M, Vallee M, Prasad GV, Lebel M, McLean D, Arnold JM, Moe GW, Howlett JG, Boulanger JM, Larochelle P, Leiter LA, Jones C, Ogilvie RI, Woo V, Kaczorowski J, Burns KD, Petrella RJ, Hiremath S, Milot A, Stone JA, Drouin D, Lavoie KL, Lamarre-Cliche M, Tremblay G, Hamet P, Fodor G, Carruthers SG, Pylypchuk GB, Burgess E, Lewanczuk R, Dresser GK, Penner SB, Hegele RA, McFarlane PA, Khara M, Pipe A, Oh P, Selby P, Sharma M, Reid DJ, Tobe SW, Padwal RS, Poirier L; Canadian Hypertension Education Program: The 2014 Canadian Hypertension Education Program recommendations for blood pressure measurement, diagnosis, assessment of risk, prevention, and treatment of hypertension. Can J Cardiol 30:485–501, 2014 24786438
603 Mancia G, Fagard R, Narkiewicz K, Redon J, Zanchetti A, Bohm M, Christiaens T, Cifkova R, De Backer G, Dominiczak A, Galderisi M, Grobbee DE, Jaarsma T, Kirchhof P, Kjeldsen SE, Laurent S, Manolis AJ, Nilsson PM, Ruilope LM, Schmieder RE, Sirnes PA, Sleight P, Viigimaa M, Waeber B, Zannad F, Redon J, Dominiczak A, Narkiewicz K, Nilsson PM, Burnier M, Viigimaa M, Ambrosioni E, Caufield M, Coca A, Olsen MH, Schmieder RE, Tsioufis C, van de Borne P, Zamorano JL, Achenbach S, Baumgartner H, Bax JJ, Bueno H, Dean V, Deaton C, Erol C, Fagard R, Ferrari R, Hasdai D, Hoes AW, Kirchhof P, Knuuti J, Kolh P, Lancellotti P, Linhart A, Nihoyannopoulos P, Piepoli MF, Ponikowski P, Sirnes PA, Tamargo JL, Tendera M, Torbicki A, Wijns W, Windecker S, Clement DL, Coca A, Gillebert TC, Tendera M, Rosei EA, Ambrosioni E, Anker SD, Bauersachs J, Hitij JB, Caulfield M, De Buyzere M, De Geest S, Derumeaux GA, Erdine S, Farsang C, Funck-Brentano C, Gerc V, Germano G, Gielen S, Haller H, Hoes AW, Jordan J, Kahan T, Komajda M, Lovic D, Mahrholdt H, Olsen MH, Ostergren J, Parati G, Perk J, Polonia J, Popescu BA, Reiner Z, Ryden L, Sirenko Y, Stanton A, Struijker-Boudier H, Tsioufis C, van de Borne P, Vlachopoulos C, Volpe M, Wood DA: 2013 ESH/ESC guidelines for the management of arterial hypertension: the Task Force for the Management of Arterial Hypertension of the European Society of Hypertension (ESH) and of the European Society of Cardiology (ESC). Eur Heart J 34:2159–2219, 2013 23771844
604 Kidney Disease: Improving Global Outcomes (KDIGO) Blood Pressure Work Group: KDIGO clinical practice guideline for the management of blood pressure in chronic kidney disease. Kidney Int Suppl 2:337–414, 2012
605 Barrett-Connor E, Grundy SM, Holdbrook MJ: Plasma lipids and diabetes mellitus in an adult community. Am J Epidemiol 115:657–663, 1982 7081197
606 Feingold KR, Grunfeld C, Pang M, Doerrler W, Krauss RM: LDL subclass phenotypes and triglyceride metabolism in non-insulin-dependent diabetes. Arterioscler Thromb 12:1496–1502, 1992 1450181
607 Quaschning T, Schomig M, Keller M, Thiery J, Nauck M, Schollmeyer P, Wanner C, Kramer-Guth A: Non-insulin-dependent diabetes mellitus and hypertriglyceridemia impair lipoprotein metabolism in chronic hemodialysis patients. J Am Soc Nephrol 10:332–341, 1999 10215333
608 Chonchol M, Cook T, Kjekshus J, Pedersen TR, Lindenfeld J: Simvastatin for secondary prevention of all-cause mortality and major coronary events in patients with mild chronic renal insufficiency. Am J Kidney Dis 49:373–382, 2007 17336698
609 Colhoun HM, Betteridge DJ, Durrington PN, Hitman GA, Neil HA, Livingstone SJ, Charlton-Menys V, DeMicco DA, Fuller JH; CARDS Investigators: Effects of atorvastatin on kidney outcomes and cardiovascular disease in patients with diabetes: an analysis from the Collaborative Atorvastatin Diabetes Study (CARDS). Am J Kidney Dis 54:810–819, 2009 19540640
610 Collins R, Armitage J, Parish S, Sleigh P, Peto R; Heart Protection Study Collaborative Group: MRC/BHF Heart Protection Study of cholesterol-lowering with simvastatin in 5963 people with diabetes: a randomised placebo-controlled trial. Lancet 361:2005–2016, 2003 12814710
611 Tonelli M, Keech A, Shepherd J, Sacks F, Tonkin A, Packard C, Pfeffer M, Simes J, Isles C, Furberg C, West M, Craven T, Curhan G: Effect of pravastatin in people with diabetes and chronic kidney disease. J Am Soc Nephrol 16:3748–3754, 2005 16251235
612 Baigent C, Landray MJ, Reith C, Emberson J, Wheeler DC, Tomson C, Wanner C, Krane V, Cass A, Craig J, Neal B, Jiang L, Hooi LS, Levin A, Agodoa L, Gaziano M, Kasiske B, Walker R, Massy ZA, Feldt-Rasmussen B, Krairittichai U, Ophascharoensuk V, Fellstrom B, Holdaas H, Tesar V, Wiecek A, Grobbee D, de Zeeuw D, Gronhagen-Riska C, Dasgupta T, Lewis D, Herrington W, Mafham M, Majoni W, Wallendszus K, Grimm R, Pedersen T, Tobert J, Armitage J, Baxter A, Bray C, Chen Y, Chen Z, Hill M, Knott C, Parish S, Simpson D, Sleight P, Young A, Collins R; SHARP Investigators: The effects of lowering LDL cholesterol with simvastatin plus ezetimibe in patients with chronic kidney disease (Study of Heart and Renal Protection): a randomised placebo-controlled trial. Lancet 377:2181–2192, 2011 21663949
613 Wanner C, Krane V, Marz W, Olschewski M, Mann JF, Ruf G, Ritz E; German Diabetes and Dialysis Study Investigators: Atorvastatin in patients with type 2 diabetes mellitus undergoing hemodialysis. N Engl J Med 353:238–248, 2005 16034009
614 Fellstrom BC, Jardine AG, Schmieder RE, Holdaas H, Bannister K, Beutler J, Chae DW, Chevaile A, Cobbe SM, Gronhagen-Riska C, De Lima JJ, Lins R, Mayer G, McMahon AW, Parving HH, Remuzzi G, Samuelsson O, Sonkodi S, Sci D, Suleymanlar G, Tsakiris D, Tesar V, Todorov V, Wiecek A, Wuthrich RP, Gottlow M, Johnsson E, Zannad F; AURORA Study Group: Rosuvastatin and cardiovascular events in patients undergoing hemodialysis. N Engl J Med 360:1395–1407, 2009 19332456
615 Holdaas H, Holme I, Schmieder RE, Jardine AG, Zannad F, Norby GE, Fellstrom BC; AURORA study group: Rosuvastatin in diabetic hemodialysis patients. J Am Soc Nephrol 22:1335–1341, 2011 21566054
616 Jardine AG, Holdaas H, Fellstrom B, Cole E, Nyberg G, Gronhagen-Riska C, Madsen S, Neumayer HH, Maes B, Ambuhl P, Olsson AG, Holme I, Fauchald P, Gimpelwicz C, Pedersen TR; ALERT Study Investigators: Fluvastatin prevents cardiac death and myocardial infarction in renal transplant recipients: post-hoc subgroup analyses of the ALERT Study. Am J Transplant 4:988–995, 2004 15147434
617 Tonelli M, Collins D, Robins S, Bloomfield H, Curhan GC; Veterans’ Affairs High-Density Lipoprotein Intervention Trial (VA-HIT) Investigators: Gemfibrozil for secondary prevention of cardiovascular events in mild to moderate chronic renal insufficiency. Kidney Int 66:1123–1130, 2004 15327407
618 Ansquer JC, Foucher C, Rattier S, Taskinen MR, Steiner G; DAIS Investigators: Fenofibrate reduces progression to microalbuminuria over 3 years in a placebo-controlled study in type 2 diabetes: results from the Diabetes Atherosclerosis Intervention Study (DAIS). Am J Kidney Dis 45:485–493, 2005 15754270
619 Davis TM, Ting R, Best JD, Donoghoe MW, Drury PL, Sullivan DR, Jenkins AJ, O’Connell RL, Whiting MJ, Glasziou PP, Simes RJ, Kesaniemi YA, Gebski VJ, Scott RS, Keech AC; Fenofibrate Intervention and Event Lower in Diabetes Study investigators: Effects of fenofibrate on renal function in patients with type 2 diabetes mellitus: the Fenofibrate Intervention and Event Lowering in Diabetes (FIELD) Study. Diabetologia 54:280–290, 2011 21052978
620 Keech A, Simes RJ, Barter P, Best J, Scott R, Taskinen MR, Forder P, Pillai A, Davis T, Glasziou P, Drury P, Kesaniemi YA, Sullivan D, Hunt D, Colman P, d’Emden M, Whiting M, Ehnholm C, Laakso M; FIELD study investigators: Effects of long-term fenofibrate therapy on cardiovascular events in 9795 people with type 2 diabetes mellitus (the FIELD study): a randomized controlled trial. Lancet 366:1849–1861, 2005 16310551
621 Wen SF, Huang TP, Moorthy AV: Effects of low-protein diet on experimental diabetic nephropathy in the rat. J Lab Clin Med 106:589–597, 1985 3903011
622 Sallstrom J, Carlström M, Olerud J, Fredholm BB, Kouzmine M, Sandler S, Persson AE: High-protein-induced glomerular hyperfiltration is independent of the tubuloglomerular feedback mechanism and nitric oxide synthases. Am J Physiol Regul Integr Comp Physiol 299:R1263–R1268, 2010 20739607
623 Wiseman MJ, Bognetti E, Dodds R, Keen H, Viberti GC: Changes in renal function in response to protein restricted diet in type 1 (insulin-dependent) diabetic patients. Diabetologia 30:154–159, 1987 3582821
624 Cohen D, Dodds R, Viberti GC: Effect of protein restriction in insulin dependent diabetics at risk of nephropathy. Br Med J (Clin Res Ed) 294:795–798, 1987
625 Pedersen MM, Mogensen CE, Jorgensen FS, Moller B, Lykke G, Pedersen O: Renal effects from limitation of high dietary protein in normoalbuminuric diabetic patients. Kidney Int Suppl 27:S115–S121, 1989 2636645
626 Dullaart RP, Beusekamp B, Meijer S, van Doormaal JJ, Sluiter WJ: Long-term effects of protein-restricted diet on albuminuria and renal function in IDDM patients without clinical nephropathy and hypertension. Diabetes Care 16:483–492, 1993 8432221
627 Tuttle KR, Puhlman ME, Cooney SK, Short RA: Effects of amino acids and glucagon on renal hemodynamics in type 1 diabetes. Am J Physiol Renal Physiol 282:F103–F112, 2002 11739118
628 Ciavarella A, Di Mizio G, Stefoni S, Borgnino LC, Vannini P: Reduced albuminuria after dietary protein restriction in insulin-dependent diabetic patients with clinical nephropathy. Diabetes Care 10:407–413, 1987 3622197
629 Evanoff G, Thompson C, Brown J, Weinman E: Prolonged dietary protein restriction in diabetic nephropathy. Arch Intern Med 149:1129–1133, 1989 2719506
630 Walker JD, Dodds RA, Murrells TJ, Bending JJ, Mattock MB, Keen H, Viberti GC: Restriction of dietary protein and progression of renal failure in diabetic nephropathy. Lancet 2:1411–1415, 1989 2574360
631 Zeller K, Whittaker E, Sullivan L, Raskin P, Jacobson HR: Effect of restricting dietary protein on the progression of renal failure in patients with insulin-dependent diabetes mellitus. N Engl J Med 324:78–84, 1991 1984187
632 Hansen HP, Tauber-Lassen E, Jensen BR, Parving HH: Effect of dietary protein restriction on prognosis in patients with diabetic nephropathy. Kidney Int 62:220–228, 2002 12081581
633 Pijls LT, de Vries H, van Eijk JT, Donker AJ: Protein restriction, glomerular filtration rate and albuminuria in patients with type 2 diabetes mellitus: a randomized trial. Eur J Clin Nutr 56:1200–1207, 2002 12494305
634 Pan Y, Guo LL, Jin HM: Low-protein diet for diabetic nephropathy: a meta-analysis of randomized controlled trials. Am J Clin Nutr 88:660–666, 2008 18779281
635 Meloni C, Tatangelo P, Cipriani S, Rossi V, Suraci C, Tozzo C, Rossini B, Cecilia A, Di Franco D, Straccialano E, Casciani CU: Adequate protein dietary restriction in diabetic and nondiabetic patients with chronic renal failure. J Ren Nutr 14:208–213, 2004 15483780
636 McGuire S: Institute of Medicine. 2010. Strategies to reduce sodium intake in the United States. Washington, DC: The National Academies Press. Adv Nutr 1:49–50, 2010
637 U.S. Department of Agriculture and U.S. Department of Health and Human Services: Dietary Guidelines for Americans, 2010. 7th Edition. Washington, DC: U.S. Government Printing Office, 2010
638 Centers for Disease Control and Prevention: Usual sodium intakes compared with current dietary guidelines—United States, 2005–2008. MMWR Morb Mortal Wkly Rep 60:1413–1417, 2011 22012113
639 Suckling RJ, He FJ, MacGregor GA: Altered dietary salt intake for preventing and treating diabetic kidney disease. Cochrane Database Syst Rev 12:CD006763, 2010
640 Sacks FM, Svetkey LP, Vollmer WM, Appel LJ, Bray GA, Harsha D, Obarzanek E, Conlin PR, Miller ER, 3rd, Simons-Morton DG, Karanja N, Lin PH; DASH-Sodium Collaborative Research Group: Effects on blood pressure of reduced dietary sodium and the Dietary Approaches to Stop Hypertension (DASH) diet. N Engl J Med 344:3–10, 2001 11136953
641 Lin J, Fung TT, Hu FB, Curhan GC: Association of dietary patterns with albuminuria and kidney function decline in older white women: a subgroup analysis from the Nurses’ Health Study. Am J Kidney Dis 57:245–254, 2011 21251540
642 Perkins BA, Rabbani N, Weston A, Ficociello LH, Adaikalakoteswari A, Niewczas M, Warram J, Krolewski AS, Thornalley P: Serum levels of advanced glycation endproducts and other markers of protein damage in early diabetic nephropathy in type 1 diabetes. PLOS ONE 7:e35655, 2012 22558190
643 RamachandraRao SP, Zhu Y, Ravasi T, McGowan TA, Toh I, Dunn SR, Okada S, Shaw MA, Sharma K: Pirfenidone is renoprotective in diabetic kidney disease. J Am Soc Nephrol 20:1765–1775, 2009 19578007
644 Shimizu T, Fukagawa M, Kuroda T, Hata S, Iwasaki Y, Nemoto M, Shirai K, Yamauchi S, Margolin SB, Shimizu F, Kurokawa K: Pirfenidone prevents collagen accumulation in the remnant kidney in rats with partial nephrectomy. Kidney Int Suppl 63:S239–S243, 1997 9407470
645 Cho ME, Smith DC, Branton MH, Penzak SR, Kopp JB: Pirfenidone slows renal function decline in patients with focal segmental glomerulosclerosis. Clin J Am Soc Nephrol 2:906–913, 2007 17702727
646 Sharma K, Ix JH, Mathew AV, Cho M, Pflueger A, Dunn SR, Francos B, Sharma S, Falkner B, McGowan TA, Donohue M, RamachandraRao S, Xu R, Fervenza FC, Kopp JB: Pirfenidone for diabetic nephropathy. J Am Soc Nephrol 22:1144–1151, 2011 21511828
647 Hagiwara S, Kantharidis P, Cooper ME: What are new avenues for renal protection, in addition to RAAS inhibition? Curr Hypertens Rep 14:100–110, 2012 22298106
648 Zieman SJ, Melenovsky V, Clattenburg L, Corretti MC, Capriotti A, Gerstenblith G, Kass DA: Advanced glycation endproduct crosslink breaker (alagebrium) improves endothelial function in patients with isolated systolic hypertension. J Hypertens 25:577–583, 2007 17278974
649 Kass DA, Shapiro EP, Kawaguchi M, Capriotti AR, Scuteri A, deGroof RC, Lakatta EG: Improved arterial compliance by a novel advanced glycation end-product crosslink breaker. Circulation 104:1464–1470, 2001 11571237
650 Shan D, Wu HM, Yuan QY, Li J, Zhou RL, Liu GJ: Pentoxifylline for diabetic kidney disease. Cochrane Database Syst Rev 2:CD006800, 2012
651 Goicoechea M, Garcia de Vinuesa S, Quiroga B, Verdalles U, Barraca D, Yuste C, Panizo N, Verde E, Munoz MA, Luno J: Effects of pentoxifylline on inflammatory parameters in chronic kidney disease patients: a randomized trial. J Nephrol 25:969–975, 2012 22241639
652 Komers R: Rho kinase inhibition in diabetic kidney disease. Curr Opin Nephrol Hypertens 20:77–83, 2011 21076299
653 Gaede P, Lund-Andersen H, Parving HH, Pedersen O: Effect of multifactorial intervention on mortality in type 2 diabetes. N Engl J Med 358:580–591, 2008 18256393
654 Sharkey TP, Root HF: Infection of the urinary tract in diabetes. JAMA 104:2231–2235, 1935
655 Baldwin AD, Root HF: Infections of the upper urinary tract in the diabetic patient. N Engl J Med 223:244–250, 1940
656 Robbins SL, Tucker AW, Jr.: Causes of death in diabetes. A report of 307 autopsied cases. N Engl J Med 231:865–868, 1944
657 Edmondson HA, Martin HE, Evans N: Necrosis of renal papillae and acute pyelonephritis in diabetes mellitus. Arch Intern Med 79:148–175, 1947
658 Aye RC: Renal papillary necrosis. Diabetes 3:124–128, 1954 13161733
659 Zhanel GG, Harding GK, Nicolle LE: Asymptomatic bacteriuria in patients with diabetes mellitus. Rev Infect Dis 13:150–154, 1991 2017615
660 Renko M, Tapanainen P, Tossavainen P, Pokka T, Uhari M: Meta-analysis of the significance of asymptomatic bacteriuria in diabetes. Diabetes Care 34:230–235, 2011 20937688
661 Ishay A, Lavi I, Luboshitzky R: Prevalence and risk factors for asymptomatic bacteriuria in women with type 2 diabetes mellitus. Diabet Med 23:185–188, 2006 16433717
662 Bonadio M, Boldrini E, Forotti G, Matteucci E, Vigna A, Mori S, Giampietro O: Asymptomatic bacteriuria in women with diabetes: influence of metabolic control. Clin Infect Dis 38:e41–e45, 2004 14999644
663 Makuyana D, Mhlabi D, Chipfupa M, Munyombwe T, Gwanzura L: Asymptomatic bacteriuria among outpatients with diabetes mellitus in an urban black population. Cent Afr J Med 48:78–82, 2002 14562524
664 Kelestimur F, Unal A, Pasaoglu H, Basar E, Kilic H, Doganay M: [Asymptomatic bacteriuria in patients with diabetes mellitus]. [Article in Turkish] Mikrobiyol Bul 24:126–132, 1990 2089231
665 Schmitt JK, Fawcett CJ, Gullickson G: Asymptomatic bacteriuria and hemoglobin A1. Diabetes Care 9:518–520, 1986 3769720
666 Abu-Bakare A, Oyaide SM: Asymptomatic bacteriuria in Nigerian diabetics. J Trop Med Hyg 89:29–32, 1986 3528518
667 Rozsai B, Lanyi E, Berki T, Soltesz G: Urinary cytokine response to asymptomatic bacteriuria in type 1 diabetic children and young adults. Pediatr Diabetes 7:153–158, 2006 16787522
668 Mendoza T, García de los Ríos M, Lafourcade M, Soto C, Durruty P, Alvo M: [Asymptomatic bacteriuria in type 2 diabetics women]. [Article in Spanish] Rev Med Chil 130:1001–1007, 2002 12434647
669 Vigg B, Rai V: Asymptomatic bacteriuria in diabetics. J Assoc Physicians India 25:57–61, 1977 924956
670 Joffe BI, Seftel HC, Distiller LA: Asymptomatic bacteriuria in diabetes mellitus. S Afr Med J 48:1306–1308, 1974 4604134
671 Rozsai B, Lanyi E, Soltesz G: Asymptomatic bacteriuria and leukocyturia in type 1 diabetic children and young adults. Diabetes Care 26:2209–2210, 2003
672 Boroumand MA, Sam L, Abbasi SH, Salarifar M, Kassaian E, Forghani S: Asymptomatic bacteriuria in type 2 Iranian diabetic women: a cross sectional study. BMC Womens Health 6:4, 2006 16504076
673 Zhanel GG, Nicolle LE, Harding GK: Prevalence of asymptomatic bacteriuria and associated host factors in women with diabetes mellitus. The Manitoba Diabetic Urinary Infection Study Group. Clin Infect Dis 21:316–322, 1995 8562738
674 Boyko EJ, Fihn SD, Scholes D, Abraham L, Monsey B: Risk of urinary tract infection and asymptomatic bacteriuria among diabetic and nondiabetic postmenopausal women. Am J Epidemiol 161:557–564, 2005 15746472
675 Sotiropoulos A, Skourtis S, Merkouris P, Peppas T, Apostolou O, Kontela E, Skliros E, Pappas S: Incidence and outcome of asymptomatic bacteriuria in females with type 2 diabetes mellitus over a 1-year follow-up period and association with risk factors. Diabet Med 22:1625–1626, 2005 16241934
676 Geerlings SE, Stolk RP, Camps MJ, Netten PM, Hoekstra JB, Bouter KP, Bravenboer B, Collet JT, Jansz AR, Hoepelman AI: Asymptomatic bacteriuria may be considered a complication in women with diabetes. Diabetes Mellitus Women Asymptomatic Bacteriuria Utrecht Study Group. Diabetes Care 23:744–749, 2000 10840989
677 Geerlings SE, Stolk RP, Camps MJ, Netten PM, Collet JT, Schneeberger PM, Hoepelman AI: Consequences of asymptomatic bacteriuria in women with diabetes mellitus. Arch Intern Med 161:1421–1427, 2001 11386891
678 Sawers JS, Todd WA, Kellett HA, Miles RS, Allan PL, Ewing DJ, Clarke BF: Bacteriuria and autonomic nerve function in diabetic women. Diabetes Care 9:460–464, 1986 3533474
679 Brauner A, Flodin U, Hylander B, Ostenson CG: Bacteriuria, bacterial virulence and host factors in diabetic patients. Diabet Med 10:550–554, 1993 8365092
680 Hansen RO: Bacteriuria in diabetic and non-diabetic out-patients. Acta Med Scand 176:721–730, 1964 14259911
681 Vejlsgaard R: Studies on urinary infection in diabetics. I. Bacteriuria in patients with diabetes mellitus and in control subjects. Acta Med Scand 179:173–182, 1966 5325464
682 Ooi BS, Chen BT, Yu M: Prevalence and site of bacteriuria in diabetes mellitus. Postgrad Med J 50:497–499, 1974 4464512
683 Jaspan JB, Mangera C, Krut LH: Bacteriuria in black diabetics. S Afr Med J 51:374–376, 1977 847559
684 Forland M, Thomas V, Shelokov A: Urinary tract infections in patients with diabetes mellitus. Studies on antibody coating of bacteria. JAMA 238:1924–1926, 1977 333137
685 Huvos A, Rocha H: Frequency of bacteriuria in patients with diabetes mellitus. A controlled study. N Engl J Med 261:1213–1216, 1959 14405661
686 O’Sullivan DJ, FitzGerald MG, Meynell MJ, Malins JM: Urinary tract infection. A comparative study in the diabetic and general populations. Br Med J 1:786–788, 1961 13730121
687 Karunajeewa H, McGechie D, Stuccio G, Stingemore N, Davis WA, Davis TM: Asymptomatic bacteriuria as a predictor of subsequent hospitalisation with urinary tract infection in diabetic adults: the Fremantle Diabetes Study. Diabetologia 48:1288–1291, 2005 15918016
688 Harding GK, Zhanel GG, Nicolle LE, Cheang M; Manitoba Diabetes Urinary Tract Infection Study Group: Antimicrobial treatment in diabetic women with asymptomatic bacteriuria. N Engl J Med 347:1576–1583, 2002 12432044
689 Ribera MC, Pascual R, Orozco D, Perez BC, Pedrera V, Gil V: Incidence and risk factors associated with urinary tract infection in diabetic patients with and without asymptomatic bacteriuria. Eur J Clin Microbiol Infect Dis 25:389–393, 2006 16767487
690 Semetkowska-Jurkiewicz E, Horoszek-Maziarz S, Galinski J, Manitius A, Krupa-Wojciechowska B: The clinical course of untreated asymptomatic bacteriuria in diabetic patients—14-year follow-up. Mater Med Pol 27:91–95, 1995 8935144
691 Czaja CA, Rutledge BN, Cleary PA, Chan K, Stapleton AE, Stamm WE; Diabetes Control and Complications Trial/Epidemiology of Diabetes Interventions and Complications Research Group: Urinary tract infections in women with type 1 diabetes mellitus: survey of female participants in the Epidemiology of Diabetes Interventions and Complications study cohort. J Urol 181:1129–1134, 2009 19152925
692 Foy MC, Estrella MM, Lucas GM, Tahir F, Fine DM, Moore RD, Atta MG: Comparison of risk factors and outcomes in HIV immune complex kidney disease and HIV-associated nephropathy. Clin J Am Soc Nephrol 8:1524–1532, 2013 23685946
693 Flandre P, Pugliese P, Cuzin L, Bagnis CI, Tack I, Cabie A, Poizot-Martin I, Katlama C, Brunet-Francois C, Yazdanpanah Y, Dellamonica P; New AIDS Data Group: Risk factors of chronic kidney disease in HIV-infected patients. Clin J Am Soc Nephrol 6:1700–1707, 2011 21566114
694 Fernando SK, Finkelstein FO, Moore BA, Weissman S: Prevalence of chronic kidney disease in an urban HIV infected population. Am J Med Sci 335:89–94, 2008 18277114
695 Nasr SH, Markowitz GS, Stokes MB, Said SM, Valeri AM, D’Agati VD: Acute postinfectious glomerulonephritis in the modern era: experience with 86 adults and review of the literature. Medicine (Baltimore) 87:21–32, 2008 18204367
696 Kim PS, Woods C, Dutcher L, Georgoff P, Rosenberg A, Mican JA, Kopp JB, Smith MA, Hadigan C: Increased prevalence of albuminuria in HIV-infected adults with diabetes. PLOS ONE 6:e24610, 2011 21931772
697 Zaidan M, Lescure FX, Brocheriou I, Dettwiler S, Guiard-Schmid JB, Pacanowski J, Rondeau E, Pialoux G, Girard PM, Ronco P, Plaisier E: Tubulointerstitial nephropathies in HIV-infected patients over the past 15 years: a clinico-pathological study. Clin J Am Soc Nephrol 8:930–938, 2013 23430209
698 Eknoyan G, Qunibi WY, Grissom RT, Tuma SN, Ayus JC: Renal papillary necrosis: an update. Medicine (Baltimore) 61:55–73, 1982 7038374
699 Abdulhayoglu S, Marble A: Necrotizing renal papillitis (papillary necrosis) in diabetes. Am J Med Sci 248:623–632, 1964 14251899
700 Griffin MD, Bergstralhn EJ, Larson TS: Renal papillary necrosis—a sixteen-year clinical experience. J Am Soc Nephrol 6:248–256, 1995 7579092

## Appendices

APPENDIX 22.1 Crude and Adjusted 1-Year Survival Probabilities Among Incident End-Stage Renal Disease Persons, by Age, Sex, Race/Ethnicity, and Primary Diagnosis, U.S., 1980–2011

CHARACTERISTICS | PERCENT
CHARACTERISTICS | 1980 | 1985 | 1990 | 1995 | 2000 | 2001 | 2002 | 2003 | 2004 | 2005 | 2006 | 2007 | 2008 | 2009 | 2010 | 2011
Crude
All | 80.7 | 77.9 | 77.3 | 77.0 | 75.3 | 75.2 | 75.2 | 75.0 | 75.5 | 75.7 | 76.3 | 76.6 | 77.2 | 77.8 | 78.2 | 79.1
Age (years)
0–4 | 91.8 | 90.6 | 83.3 | 86.3 | 82.2 | 88.4 | 89.8 | 88.6 | 88.5 | 90.1 | 87.1 | 92.3 | 91.3 | 88.7 | 93.8 | 91.8
5–9 | 93.5 | 93.9 | 95.8 | 95.7 | 96.2 | 96.6 | 95.0 | 95.9 | 97.9 | 97.9 | 96.2 | 96.8 | 94.2 | 94.2 | 97.9 | 98.5
10–14 | 96.6 | 98.1 | 96.4 | 97.4 | 97.4 | 97.7 | 97.3 | 98.4 | 98.3 | 98.1 | 98.6 | 99.3 | 98.9 | 98.9 | 98.5 | 98.9
15–19 | 96.7 | 97.4 | 95.8 | 97.6 | 98.0 | 97.0 | 97.6 | 96.8 | 96.7 | 96.6 | 97.4 | 97.7 | 97.6 | 96.9 | 98.0 | 97.8
20–29 | 92.7 | 93.2 | 92.8 | 91.5 | 93.7 | 94.5 | 93.7 | 93.6 | 93.5 | 93.3 | 94.0 | 94.2 | 94.2 | 94.5 | 94.9 | 94.6
30–39 | 89.5 | 90.3 | 89.6 | 88.5 | 90.7 | 91.0 | 91.2 | 91.3 | 91.7 | 91.7 | 92.8 | 92.7 | 92.1 | 92.9 | 93.4 | 93.9
40–49 | 89.1 | 89.0 | 88.9 | 88.4 | 89.0 | 88.7 | 88.4 | 88.2 | 88.7 | 88.6 | 89.3 | 89.7 | 89.8 | 90.4 | 91.1 | 91.6
50–59 | 84.8 | 83.2 | 84.1 | 85.0 | 84.6 | 84.4 | 84.8 | 84.1 | 84.9 | 84.6 | 85.3 | 85.5 | 85.9 | 86.2 | 86.3 | 87.2
60–64 | 78.4 | 76.4 | 77.2 | 78.9 | 78.9 | 79.7 | 79.3 | 80.0 | 80.4 | 80.8 | 81.1 | 81.2 | 82.3 | 82.2 | 82.4 | 83.6
65–69 | 70.3 | 68.9 | 72.5 | 74.5 | 73.9 | 74.4 | 74.4 | 74.8 | 74.6 | 75.5 | 76.4 | 76.2 | 76.7 | 77.8 | 77.7 | 78.4
70–74 | 65.5 | 64.1 | 67.1 | 69.2 | 68.5 | 68.3 | 68.3 | 68.6 | 69.0 | 69.5 | 70.6 | 70.8 | 70.9 | 72.3 | 73.1 | 73.6
75–79 | 58.6 | 62.2 | 62.1 | 62.7 | 62.5 | 62.7 | 63.0 | 62.6 | 63.1 | 63.8 | 63.7 | 64.7 | 65.9 | 66.1 | 67.0 | 68.3
80–84 | 53.7 | 55.0 | 56.0 | 57.6 | 55.1 | 55.2 | 56.5 | 56.9 | 57.2 | 57.1 | 57.1 | 57.8 | 59.7 | 60.6 | 61.6 | 61.7
≥85 | 52.9 | 46.2 | 49.3 | 50.3 | 47.3 | 46.9 | 47.5 | 46.1 | 47.4 | 48.6 | 48.1 | 50.5 | 51.5 | 51.5 | 52.2 | 54.1
Sex
Men | 80.6 | 77.8 | 77.1 | 76.9 | 75.9 | 75.7 | 75.7 | 75.5 | 75.8 | 76.2 | 76.7 | 76.9 | 77.3 | 78.0 | 78.3 | 79.3
Women | 80.9 | 78.1 | 77.6 | 77.0 | 74.6 | 74.7 | 74.5 | 74.5 | 75.1 | 75.1 | 75.7 | 76.3 | 77.1 | 77.6 | 78.0 | 78.7
Race/ethnicity
White | 78.9 | 75.5 | 74.5 | 74.2 | 72.3 | 72.2 | 72.1 | 72.2 | 72.6 | 73.0 | 73.5 | 73.8 | 74.4 | 74.8 | 75.2 | 76.2
Black | 85.1 | 83.0 | 82.6 | 81.3 | 79.8 | 80.2 | 80.1 | 79.5 | 80.1 | 80.3 | 81.2 | 81.7 | 82.2 | 82.9 | 83.3 | 84.1
American Indian | 93.8 | 80.8 | 84.4 | 84.8 | 78.4 | 84.6 | 86.0 | 83.6 | 82.9 | 84.9 | 85.3 | 86.8 | 83.2 | 87.0 | 88.9 | 87.4
Asian | 100.0 | 82.5 | 86.1 | 83.9 | 85.0 | 84.0 | 84.2 | 84.2 | 84.8 | 84.4 | 84.4 | 84.0 | 85.6 | 87.2 | 86.6 | 86.8
Other | 72.2 | 74.9 | 77.1 | 78.8 | 80.1 | 78.7 | 78.8 | 78.1 | 79.3 | 76.9 | 74.0 | 71.8 | 67.2 | 69.9 | 64.0 | 70.6
Hispanic^*^ | | | | | 81.9 | 81.9 | 81.6 | 81.8 | 82.4 | 82.3 | 83.5 | 83.8 | 84.1 | 84.8 | 85.0 | 85.2
Non-Hispanic^*^ | | | | | 74.2 | 74.3 | 74.2 | 74.1 | 74.5 | 74.7 | 75.2 | 75.5 | 76.1 | 76.7 | 77.1 | 78.0
Primary diagnosis
Diabetes | 78.3 | 75.2 | 76.7 | 77.6 | 76.1 | 76.4 | 76.4 | 76.7 | 77.2 | 77.2 | 78.2 | 78.3 | 79.1 | 80.0 | 80.2 | 81.0
HTN | 83.6 | 76.2 | 74.3 | 74.9 | 72.7 | 72.4 | 72.9 | 72.6 | 72.8 | 73.2 | 73.6 | 74.4 | 75.2 | 75.3 | 76.6 | 77.4
GN | 91.8 | 87.0 | 85.3 | 86.1 | 86.3 | 86.4 | 86.5 | 86.6 | 87.3 | 87.0 | 87.5 | 88.3 | 89.1 | 89.0 | 89.0 | 89.8
Other cause | 77.2 | 76.3 | 76.9 | 72.4 | 70.6 | 70.4 | 69.3 | 68.8 | 69.3 | 70.5 | 70.8 | 70.9 | 70.9 | 71.7 | 71.5 | 72.6
Adjusted^†^
All | 72.4 | 71.7 | 73.7 | 75.1 | 75.0 | 75.2 | 75.3 | 75.2 | 75.7 | 75.9 | 76.4 | 76.7 | 77.3 | 77.9 | 78.3 | 79.1
Age (years)
0–19 | 92.5 | 92.8 | 90.1 | 92.4 | 92.7 | 94.0 | 92.9 | 94.6 | 93.3 | 95.3 | 93.9 | 95.9 | 96.8 | 94.3 | 97.9 | 97.1
20–44 | 89.0 | 90.0 | 89.5 | 88.5 | 90.3 | 90.6 | 90.6 | 90.5 | 91.0 | 91.1 | 91.7 | 92.1 | 91.9 | 92.5 | 93.1 | 93.6
45–64 | 81.6 | 80.8 | 82.5 | 83.9 | 84.1 | 84.2 | 84.2 | 83.9 | 84.5 | 84.4 | 85.0 | 85.1 | 85.7 | 85.9 | 86.0 | 86.8
65–74 | 67.8 | 66.0 | 70.0 | 72.1 | 71.6 | 71.8 | 71.7 | 72.2 | 72.3 | 73.0 | 74.0 | 74.0 | 74.3 | 75.6 | 75.9 | 76.6
≥75 | 58.4 | 58.9 | 59.0 | 59.7 | 58.1 | 58.2 | 58.7 | 58.3 | 58.9 | 59.2 | 59.1 | 60.0 | 61.3 | 61.5 | 62.4 | 63.4
Sex
Men | 72.0 | 70.8 | 72.7 | 74.2 | 75.1 | 75.1 | 75.3 | 75.2 | 75.5 | 76.0 | 76.4 | 76.7 | 77.1 | 77.7 | 78.2 | 79.0
Women | 72.7 | 72.7 | 74.8 | 76.0 | 74.9 | 75.3 | 75.2 | 75.3 | 75.8 | 75.8 | 76.3 | 76.8 | 77.6 | 78.0 | 78.5 | 79.2
Race/ethnicity
White | 68.9 | 68.9 | 71.5 | 73.6 | 73.7 | 73.8 | 73.9 | 74.1 | 74.5 | 74.7 | 75.2 | 75.4 | 76.0 | 76.2 | 76.8 | 77.5
Black | 79.6 | 77.5 | 78.0 | 77.4 | 76.7 | 77.3 | 77.2 | 76.5 | 77.0 | 77.3 | 78.3 | 78.8 | 79.5 | 80.4 | 80.9 | 81.9
American Indian | 89.9 | 75.7 | 81.0 | 81.8 | 77.8 | 81.8 | 84.0 | 81.4 | 80.6 | 82.4 | 82.2 | 84.8 | 80.8 | 85.1 | 86.9 | 85.2
Asian | ^‡^ | 75.1 | 82.6 | 82.3 | 84.2 | 83.6 | 83.9 | 84.2 | 84.8 | 84.4 | 84.3 | 84.1 | 85.7 | 87.3 | 86.7 | 87.1
Other | 64.5 | 66.3 | 64.0 | 75.9 | 77.6 | 76.5 | 76.1 | 76.0 | 77.1 | 75.4 | 73.4 | 71.7 | 66.5 | 70.3 | 65.2 | 71.4
Primary diagnosis
Diabetes | 70.1 | 68.4 | 72.9 | 75.5 | 75.4 | 75.9 | 75.9 | 76.2 | 76.8 | 76.7 | 77.6 | 77.8 | 78.5 | 79.4 | 79.7 | 80.4
HTN | 79.2 | 75.1 | 75.5 | 77.0 | 76.3 | 76.1 | 76.7 | 76.3 | 76.6 | 76.9 | 77.1 | 77.6 | 78.3 | 78.2 | 79.3 | 80.0
GN | 84.0 | 79.4 | 78.2 | 80.3 | 81.0 | 80.7 | 81.3 | 81.2 | 81.8 | 81.6 | 82.3 | 83.1 | 84.1 | 84.2 | 84.3 | 85.1
Other cause | 71.4 | 71.7 | 72.6 | 69.3 | 68.8 | 68.7 | 67.9 | 67.3 | 67.8 | 69.0 | 69.3 | 69.6 | 69.7 | 70.6 | 70.5 | 71.5

Censored at lost to follow-up or recovery of function from day 1 to 1 year by age, sex, race, ethnicity, and primary diagnosis. GN, glomerulonephritis; HTN, hypertension.

* The Centers for Medicare and Medicaid Services began collecting Hispanic ethnicity data in April 1995.

† Adjusted for age, sex, race, and primary cause of end-stage renal disease.

‡ Values for cells with 10 or fewer patients are suppressed.

SOURCE: Reference 1

APPENDIX 22.2 Crude and Adjusted 5-Year Survival Probabilities Among Incident End-Stage Renal Disease Persons, by Age, Sex, Race/Ethnicity, and Primary Diagnosis, U.S., 1980–2007

CHARACTERISTICS | PERCENT
CHARACTERISTICS | 1980 | 1985 | 1990 | 1995 | 2000 | 2001 | 2002 | 2003 | 2004 | 2005 | 2006 | 2007
Crude
All | 42.3 | 36.7 | 36.8 | 36.0 | 35.7 | 36.3 | 36.6 | 37.1 | 38.3 | 39.3 | 40.1 | 41.0
Age (years)
0–4 | 82.2 | 80.3 | 71.7 | 76.3 | 70.7 | 80.7 | 80.1 | 80.5 | 78.5 | 82.1 | 79.6 | 82.6
5–9 | 88.8 | 89.6 | 90.7 | 92.7 | 89.7 | 90.3 | 90.4 | 92.5 | 94.4 | 95.0 | 89.0 | 94.3
10–14 | 88.6 | 90.4 | 90.6 | 92.0 | 93.0 | 91.5 | 89.9 | 92.3 | 93.9 | 95.8 | 96.7 | 95.2
15–19 | 89.8 | 86.4 | 88.1 | 90.2 | 88.7 | 89.0 | 89.7 | 89.2 | 88.4 | 90.0 | 89.5 | 90.6
20–29 | 77.1 | 75.5 | 77.1 | 76.9 | 79.0 | 79.9 | 80.1 | 81.0 | 81.8 | 80.2 | 82.2 | 81.0
30–39 | 64.3 | 63.7 | 67.1 | 66.6 | 70.1 | 70.3 | 71.6 | 71.7 | 73.3 | 73.6 | 74.2 | 74.5
40–49 | 54.3 | 55.9 | 58.2 | 58.9 | 60.3 | 61.2 | 60.3 | 61.0 | 62.5 | 64.1 | 64.7 | 65.7
50–59 | 41.2 | 37.9 | 42.8 | 44.9 | 47.5 | 48.3 | 48.9 | 49.3 | 51.1 | 52.1 | 52.6 | 54.2
60–64 | 31.2 | 26.3 | 30.5 | 32.8 | 35.9 | 36.8 | 38.5 | 39.8 | 40.7 | 41.6 | 42.2 | 44.1
65–69 | 21.0 | 18.7 | 22.5 | 24.4 | 27.7 | 29.4 | 30.3 | 31.6 | 32.9 | 33.7 | 34.9 | 35.9
70–74 | 15.3 | 14.6 | 16.6 | 18.6 | 20.4 | 21.5 | 22.2 | 22.6 | 23.6 | 25.6 | 26.7 | 27.6
75–79 | 11.1 | 9.0 | 10.6 | 12.9 | 14.9 | 14.9 | 15.4 | 16.1 | 16.9 | 18.0 | 18.8 | 19.7
80–84 | 4.8 | 6.8 | 8.6 | 8.5 | 8.5 | 9.7 | 10.5 | 10.8 | 11.3 | 12.5 | 12.8 | 13.2
≥85 | 5.5 | 2.1 | 4.6 | 4.8 | 4.6 | 5.6 | 5.5 | 5.1 | 6.4 | 6.0 | 6.6 | 7.1
Sex
Men | 42.2 | 36.6 | 37.5 | 37.4 | 36.7 | 37.3 | 37.5 | 38.0 | 39.0 | 39.9 | 41.0 | 41.4
Women | 42.3 | 36.8 | 35.9 | 34.4 | 34.6 | 35.1 | 35.4 | 36.0 | 37.4 | 38.5 | 39.0 | 40.6
Race/ethnicity
White | 41.2 | 35.5 | 33.2 | 31.6 | 31.4 | 32.0 | 32.2 | 32.6 | 33.8 | 35.0 | 35.5 | 36.3
Black | 45.1 | 38.9 | 43.5 | 43.2 | 42.7 | 43.4 | 43.7 | 44.3 | 45.9 | 46.8 | 48.6 | 49.7
American Indian | 54.9 | 37.9 | 40.9 | 44.8 | 39.3 | 47.0 | 45.5 | 48.2 | 46.3 | 50.0 | 51.1 | 50.3
Asian | 94.0 | 42.8 | 49.7 | 45.9 | 48.4 | 50.1 | 50.6 | 50.7 | 52.5 | 52.3 | 53.1 | 53.9
Other | 25.9 | 47.0 | 46.9 | 38.3 | 42.6 | 40.8 | 42.2 | 43.8 | 44.1 | 42.9 | 28.8 | 25.0
Hispanic^*^ | | | | | 45.2 | 46.3 | 47.1 | 48.2 | 49.6 | 50.5 | 51.7 | 52.8
Non-Hispanic^*^ | | | | | 34.0 | 34.8 | 35.0 | 35.4 | 36.5 | 37.6 | 38.2 | 39.1
Primary diagnosis
Diabetes | 32.0 | 26.1 | 28.2 | 29.2 | 30.5 | 32.0 | 32.3 | 33.3 | 34.7 | 35.8 | 36.9 | 37.8
HTN | 45.2 | 32.3 | 32.7 | 33.5 | 32.9 | 32.4 | 33.1 | 33.6 | 34.4 | 35.0 | 36.1 | 37.7
GN | 66.3 | 54.1 | 56.2 | 57.1 | 59.2 | 59.9 | 60.6 | 62.0 | 62.6 | 63.4 | 64.0 | 65.5
Other cause | 37.4 | 40.6 | 44.3 | 40.8 | 39.8 | 40.4 | 39.7 | 39.6 | 41.2 | 42.8 | 42.9 | 43.4
Adjusted^†^
All | 28.8 | 27.2 | 31.0 | 33.1 | 35.5 | 36.5 | 37.0 | 37.7 | 38.8 | 39.7 | 40.5 | 41.4
Age (years)
0–19 | 80.6 | 77.3 | 78.4 | 81.5 | 81.4 | 84.7 | 80.6 | 86.2 | 83.0 | 89.4 | 85.0 | 87.8
20–44 | 61.5 | 62.7 | 66.3 | 65.7 | 68.0 | 68.5 | 69.1 | 69.4 | 71.2 | 71.7 | 72.7 | 73.3
45–64 | 36.0 | 34.1 | 40.1 | 44.0 | 47.3 | 48.2 | 48.8 | 49.4 | 50.8 | 51.8 | 52.4 | 53.7
65–74 | 18.3 | 16.2 | 19.6 | 21.8 | 24.7 | 26.3 | 26.9 | 28.0 | 29.2 | 30.6 | 31.8 | 32.7
≥75 | 9.8 | 8.1 | 9.5 | 10.6 | 11.5 | 12.2 | 12.5 | 12.8 | 13.7 | 14.4 | 15.0 | 15.4
Sex
Men | 28.5 | 25.9 | 30.5 | 33.1 | 35.4 | 36.4 | 36.9 | 37.6 | 38.7 | 39.6 | 40.5 | 41.1
Women | 28.9 | 28.7 | 31.5 | 33.1 | 35.6 | 36.6 | 37.1 | 37.7 | 38.9 | 39.9 | 40.4 | 41.7
Race/ethnicity
White | 25.9 | 25.7 | 28.5 | 30.9 | 33.8 | 34.9 | 35.4 | 35.9 | 37.2 | 38.1 | 38.5 | 39.3
Black | 33.7 | 28.9 | 34.9 | 36.3 | 37.4 | 38.4 | 38.8 | 39.3 | 40.5 | 41.6 | 43.4 | 44.5
American Indian | 40.3 | 29.8 | 33.9 | 39.2 | 38.9 | 41.8 | 41.4 | 44.7 | 42.7 | 45.8 | 45.2 | 46.6
Asian | 81.1 | 29.9 | 40.6 | 42.2 | 47.0 | 49.2 | 50.0 | 50.9 | 52.3 | 52.3 | 53.1 | 54.4
Other | 18.9 | 35.0 | 26.7 | 33.1 | 38.1 | 37.3 | 37.6 | 40.6 | 40.6 | 40.6 | 28.8 | 25.3
Primary diagnosis
Diabetes | 22.4 | 19.3 | 24.0 | 27.3 | 30.5 | 32.4 | 32.5 | 33.7 | 34.9 | 36.0 | 36.7 | 37.7
HTN | 37.2 | 31.7 | 34.9 | 36.8 | 38.5 | 38.3 | 39.5 | 39.6 | 40.5 | 41.2 | 42.1 | 43.0
GN | 43.8 | 37.1 | 40.9 | 43.7 | 46.7 | 47.1 | 48.7 | 49.7 | 49.8 | 51.1 | 51.9 | 53.0
Other cause | 29.4 | 32.4 | 36.4 | 35.9 | 36.6 | 37.4 | 37.1 | 36.9 | 38.8 | 40.0 | 40.4 | 41.1

Censored at lost to follow-up or recovery of function, from day 1 to one year, by age, sex, race/ethnicity, and primary diagnosis. GN, glomerulonephritis; HTN, hypertension.

* The Centers for Medicare and Medicaid Services began collecting Hispanic ethnicity data in April 1995.

† Adjusted for age, sex, race, and primary cause of end-stage renal disease.

SOURCE: Reference 1

APPENDIX 22.3 Adjusted Survival Probabilities Among Persons Initiating End-Stage Renal Disease Treatment in 2007, U.S.

2007 COHORT | PERCENT
2007 COHORT | 3 Months | 12 Months | 24 Months | 36 Months | 60 Months
Treatment
Dialysis | 91.7 | 76.4 | 64.4 | 54.9 | 40.4
Hemodialysis | 91.4 | 75.8 | 63.7 | 54.2 | 39.8
Peritoneal dialysis | 96.9 | 87.6 | 74.9 | 64.7 | 49.2
Deceased-donor transplant | 96.8 | 92.5 | 88.4 | 84.1 | 73.7
Living donor transplant | 99.2 | 97.6 | 95.5 | 93.0 | 87.0
Age (years)
0–19 | 98.4 | 95.5 | 91.9 | 89.7 | 87.0
20–44 | 97.7 | 91.9 | 85.9 | 81.0 | 73.0
45–64 | 95.4 | 85.0 | 75.7 | 67.3 | 53.3
65–74 | 91.0 | 74.2 | 60.8 | 49.9 | 33.0
≥75 | 84.6 | 60.4 | 43.4 | 31.5 | 15.8
Sex
Men | 91.7 | 76.9 | 64.9 | 55.4 | 41.3
Women | 91.9 | 76.8 | 65.2 | 55.9 | 41.6
Race
White | 91.0 | 75.2 | 62.9 | 53.3 | 38.8
Black/African American | 93.2 | 79.1 | 68.0 | 59.0 | 45.3
American Indian | 95.1 | 84.7 | 71.6 | 61.6 | 46.8
Asian | 94.6 | 83.8 | 74.9 | 66.9 | 53.7
Other | 91.1 | 72.1 | 55.4 | 44.2 | 26.1
Primary cause of ESRD
Diabetes | 92.7 | 77.6 | 64.4 | 53.7 | 37.2
Hypertension | 92.0 | 77.9 | 66.4 | 57.4 | 43.6
Glomerulonephritis | 94.3 | 83.4 | 73.9 | 66.3 | 53.8
Other | 88.2 | 70.0 | 59.6 | 52.0 | 41.6

Adjusted survival probabilities, from day 1, in the ESRD population. Reference population: incident ESRD persons in 2011. Adjusted for age, sex, race, Hispanic ethnicity, and primary diagnosis. ESRD, end-stage renal disease.

SOURCE: Reference 1

APPENDIX 22.4 Crude Mortality Rates Among Prevalent End-Stage Renal Disease Persons With Diabetes, by Age, Sex, and Race/Ethnicity, U.S., 2012

AGE (YEARS) | ALL | | | | | | MEN | | | | | | WOMEN
AGE (YEARS) | All | Non-Hispanic | | | | Hisp | All | Non-Hispanic | | | | Hisp | All | Non-Hispanic | | | | Hisp
AGE (YEARS) | All | White | Af Am | Am Ind | Asian | Hisp | All | White | Af Am | Am Ind | Asian | Hisp | All | White | Af Am | Am Ind | Asian | Hisp
All | 170.8 | 211.0 | 146.6 | 138.3 | 140.3 | 139.3 | 166.6 | 208.3 | 136.8 | 133.9 | 135.0 | 133.1 | 176.0 | 214.8 | 156.5 | 142.5 | 147.2 | 147.7
0–19 | 31.6 | 33.3 | 39.4 | 33.9 | 20.2 | 23.1 | 28.6 | 31.0 | 34.1 | 30.7 | 19.3 | 20.9 | 34.0 | 36.0 | 42.1 | 33.9 | 21.1 | 24.5
20–29 | 71.0 | 73.6 | 81.2 | 64.7 | 41.5 | 50.1 | 60.1 | 66.9 | 65.7 | 62.5 | 39.9 | 45.2 | 78.5 | 79.0 | 90.3 | 65.6 | 42.9 | 54.3
30–39 | 70.4 | 80.1 | 73.0 | 64.7 | 45.7 | 54.8 | 66.0 | 77.0 | 65.8 | 62.2 | 46.2 | 52.4 | 75.4 | 84.0 | 80.4 | 66.6 | 45.2 | 58.0
40–49 | 80.5 | 90.2 | 82.8 | 80.0 | 62.0 | 62.4 | 77.1 | 87.9 | 77.0 | 79.0 | 60.6 | 60.7 | 85.8 | 93.8 | 90.6 | 81.3 | 64.5 | 65.6
50–59 | 114.7 | 133.1 | 112.2 | 107.1 | 89.9 | 93.0 | 111.5 | 130.0 | 107.7 | 105.7 | 90.1 | 90.5 | 119.3 | 138.3 | 117.7 | 108.6 | 89.7 | 97.3
60–64 | 150.8 | 184.8 | 130.9 | 135.8 | 116.0 | 129.8 | 148.7 | 182.9 | 126.0 | 134.4 | 112.5 | 127.6 | 153.6 | 187.4 | 136.2 | 137.2 | 121.0 | 132.8
65–69 | 184.0 | 220.9 | 162.7 | 166.9 | 134.2 | 157.1 | 186.1 | 221.5 | 163.3 | 168.8 | 134.7 | 156.9 | 181.6 | 220.1 | 162.3 | 165.2 | 133.5 | 157.4
70–74 | 224.9 | 274.1 | 189.0 | 211.9 | 163.3 | 196.3 | 229.0 | 274.7 | 190.8 | 220.5 | 164.8 | 195.3 | 220.4 | 273.3 | 187.5 | 206.3 | 161.5 | 197.3
75–79 | 281.5 | 338.1 | 239.3 | 233.0 | 207.2 | 244.2 | 291.7 | 347.4 | 234.3 | 247.7 | 212.2 | 250.6 | 271.5 | 326.6 | 242.8 | 224.3 | 202.3 | 237.9
80–84 | 357.3 | 426.2 | 281.7 | 292.6 | 272.2 | 309.8 | 382.3 | 446.1 | 290.2 | 307.6 | 280.7 | 324.7 | 334.0 | 402.6 | 276.6 | 283.0 | 265.0 | 296.3
≥85 | 446.8 | 525.4 | 358.5 | 335.5 | 342.8 | 384.6 | 478.2 | 548.9 | 361.7 | 354.1 | 356.2 | 404.4 | 419.2 | 498.1 | 356.9 | 327.2 | 331.9 | 367.5

Rates are per 1,000 patient-years at risk, period prevalent ESRD persons, 2012, by age as of January 1, sex, and race. Af Am, African American; Am Ind, American Indian; ESRD, end-stage renal disease; Hisp, Hispanic.

SOURCE: Reference 1

APPENDIX 22.5 Crude and Adjusted Annual Mortality Rates Among End-Stage Renal Disease Persons, by Age, Sex, Race, Primary Diagnosis, and Patient Vintage, U.S., 1985–2012

CHARACTERISTICS | DEATHS PER 1,000 PATIENT-YEARS AT RISK
CHARACTERISTICS | 1985 | 1990 | 1995 | 2000 | 2005 | 2006 | 2007 | 2008 | 2009 | 2010 | 2011 | 2012
Crude | 185.5 | 185.0 | 186.6 | 187.5 | 175.9 | 171.9 | 165.0 | 159.1 | 155.8 | 150.5 | 147.0 | 137.9
Adjusted | 242.1 | 221.6 | 203.8 | 194.3 | 177.5 | 172.8 | 165.9 | 159.8 | 156.1 | 150.5 | 147.0 | 137.8
Age (years)
0–19 | 48.3 | 38.0 | 33.6 | 31.2 | 30.4 | 28.3 | 23.2 | 22.1 | 20.9 | 23.5 | 20.3 | 18.0
20–44 | 81.4 | 75.2 | 74.3 | 66.7 | 62.7 | 61.2 | 59.1 | 56.4 | 55.6 | 52.8 | 50.8 | 47.4
45–64 | 185.3 | 161.4 | 144.1 | 133.0 | 121.8 | 118.9 | 113.6 | 109.3 | 106.7 | 102.8 | 100.8 | 95.0
65–74 | 332.0 | 303.3 | 272.0 | 258.0 | 229.4 | 219.9 | 209.0 | 200.6 | 196.5 | 189.5 | 183.2 | 171.5
≥75 | 443.6 | 433.1 | 412.8 | 414.0 | 384.7 | 376.4 | 365.0 | 351.7 | 342.6 | 329.7 | 322.1 | 301.5
Sex
Men | 251.3 | 230.8 | 206.6 | 193.7 | 177.9 | 173.1 | 166.3 | 160.4 | 157.3 | 151.7 | 148.2 | 139.2
Women | 230.9 | 210.2 | 200.7 | 195.5 | 177.4 | 173.0 | 166.0 | 159.6 | 155.0 | 149.4 | 145.7 | 136.5
Race
White | 256.8 | 233.5 | 215.9 | 203.9 | 183.0 | 178.6 | 171.8 | 166.1 | 162.7 | 157.9 | 155.4 | 146.2
Black/African American | 220.7 | 204.5 | 189.3 | 183.8 | 176.2 | 171.0 | 163.2 | 156.2 | 151.6 | 144.3 | 138.5 | 129.3
American Indian | 206.5 | 193.1 | 173.3 | 175.4 | 158.4 | 154.3 | 147.6 | 147.7 | 149.8 | 140.7 | 132.7 | 126.4
Asian | 181.4 | 168.7 | 147.1 | 142.2 | 125.0 | 120.6 | 118.1 | 109.9 | 107.4 | 102.2 | 100.4 | 94.5
Other | 305.6 | 291.3 | 219.6 | 194.8 | 173.9 | 165.0 | 151.9 | 150.0 | 141.7 | 133.5 | 125.9 | 101.7
Primary cause of ESRD
Diabetes | 296.5 | 261.8 | 239.0 | 227.6 | 203.5 | 198.3 | 189.9 | 182.6 | 178.2 | 172.6 | 169.5 | 158.4
HTN | 211.4 | 207.4 | 194.5 | 184.0 | 170.6 | 167.4 | 161.5 | 156.8 | 152.8 | 147.5 | 143.0 | 133.9
GN | 164.9 | 167.9 | 151.6 | 142.2 | 125.3 | 121.0 | 116.6 | 110.3 | 109.4 | 105.0 | 100.6 | 94.3
Other cause | 222.2 | 194.3 | 180.4 | 176.7 | 170.1 | 163.9 | 157.0 | 150.8 | 147.1 | 140.0 | 136.4 | 129.6
Patient vintage
<2 years | 279.2 | 251.8 | 230.1 | 218.6 | 205.1 | 200.8 | 193.9 | 187.7 | 184.0 | 176.9 | 172.0 | 160.9
2-<5 years | 234.4 | 219.5 | 207.5 | 192.1 | 172.0 | 167.5 | 160.0 | 153.7 | 150.1 | 145.6 | 142.3 | 135.5
≥5 years | 205.0 | 188.2 | 170.0 | 166.9 | 149.1 | 143.7 | 137.2 | 131.3 | 127.5 | 122.6 | 120.3 | 111.7

Death rates per 1,000 patient-years at risk, period prevalent persons, by age, sex, race, ethnicity, primary diagnosis, and patient vintage. For each of the variables, rates are adjusted for the remaining variables. Overall mortality rates are adjusted for age, sex, race, primary diagnosis, and vintage. Reference population: 2011 prevalent ESRD population. ESRD, end-stage renal disease; GN, glomerulonephritis; HTN, hypertension.

SOURCE: Reference 1