# CHAPTER 14 Genetics of Type 2 Diabetes

## Summary

Type 2 diabetes is thought to result from a combination of environmental, behavioral, and genetic factors, with the heritability of type 2 diabetes estimated to be in the range of 25% to 72% based on family and twin studies. Since early 2007, genome-wide association studies (GWAS) have led to an explosion of data for the genetics of type 2 diabetes and related traits. These GWAS have occurred on the background of genotyping arrays populated by common single nucleotide polymorphisms (SNPs), deployed in various cohorts that have coalesced to form large international consortia. As a result, a list of genetic loci that influence type 2 diabetes and quantitative glycemic traits has begun to accumulate. Over 100 type 2 diabetes-associated loci have been identified, in addition to others involved in determining quantitative glycemic traits, such as insulin resistance. However, no variant that is widely shared across populations has been found to have a stronger effect than the rs7903146 SNP in TCF7L2, which itself has only a modest effect (odds ratio ~1.4). Nonetheless, GWAS findings have illustrated novel pathways, pointed toward fundamental biology, drawn attention to the role of beta cell dysfunction in type 2 diabetes, confirmed prior epidemiologic observations, and provided possible targets for pharmacotherapy and pharmacogenetic clinical trials.

On the other hand, the causal variants have only been identified for a handful of these loci, a substantial proportion of the heritability of these phenotypes remains unexplained, and this has tempered expectations with regard to their use in clinical prediction. Together, the approximately 100 loci associated with type 2 diabetes thus far explain ~10%–15% of the genetic predisposition to the disease. Limitations of early GWAS included insufficient sample sizes to detect small effects, a nearly exclusive focus on populations of European descent, an imperfect capture of uncommon genetic variants, an incomplete ascertainment of alternate (non-SNP) forms of genetic variation, and the lack of exploration of additional genetic models.

As the community embraces complementary approaches that include systematic fine-mapping, custom-made replication, denser genotyping arrays, platforms that focus on functional variation, next-generation sequencing techniques, systems biology approaches, and expansion to non-European populations, the coming years will witness exponential growth in the understanding of the genetic architecture of metabolic phenotypes. Whether these findings prove useful in disease prediction or therapeutic decision-making must be tested in rigorously designed clinical trials.

## Type 2 Diabetes as a Genetic Disease

The explosive parallel growth in the prevalence of the related metabolic disorders of obesity and type 2 diabetes in much of the developed and developing worlds over the past few decades is almost certainly driven by environmental and behavioral factors, since genetic components do not change in an appreciable manner over such a short time period. However, several lines of evidence suggest that variation in DNA sequence does contribute to type 2 diabetes risk. First, twin studies have shown that concordance for type 2 diabetes is greater for monozygotic twins (who share 100% of their DNA sequence) than for dizygotic twins (who, like siblings, share approximately 50% of their DNA sequence) (1,2,3,4,5). Second, the incidence of diabetes is much higher in certain racial/ethnic groups, despite an environment that is relatively comparable to that of neighboring populations (6,7,8). Third, family history is an independent risk factor for the development of diabetes in population studies (9,10). And fourth, rare familial forms of diabetes, caused by mutations in single genes (hence, termed monogenic or Mendelian), prove that single base pair changes in the coding regions of key genes, which lead to alterations in protein sequence and function, are sufficient to cause hyperglycemia in the diabetic range (11,12). Consistent with this notion, the heritability of type 2 diabetes estimated in a set of Scandinavian families ranges from 25% to 69% (13), and a large international meta-analysis of twin studies has reported a heritability estimate as high as 72% (14).

Taken together, these observations illustrate that rapid changes in the global epidemiology of type 2 diabetes are likely caused by environmental and behavioral factors overlaid on a background of genetic predisposition. This genetic predisposition may vary across populations, in some measure due to their divergent genetic history and unequal selection pressures in specific geographic regions. Thus, it is well known and described elsewhere in this volume (see Chapter 13 Risk Factors for Type 2 Diabetes) that the risk of type 2 diabetes differs in the various ethnic groups that compose the U.S. population, and the presumption is that some of these differences are genetic in nature (15).

Why is genetic exploration relevant? Regardless of whether genetic predictors become useful markers of disease onset or progression in clinical practice, the identification of genetic variants associated with type 2 diabetes illuminates pathogenic mechanisms from which therapeutic windows may emerge. Because germline genetic variation always predates the onset of disease, the arrow of time establishes a causal relationship that is not evident with other biologic associations. Thus, the genetic approach has a unique opportunity to shed light on the pathophysiology of diabetes in its various manifestations, helping unravel its clinical heterogeneity and potentially refine therapeutic strategies.

## Discovery of Type 2 Diabetes Genes

Before the sequencing of the human genome was accomplished, genetic mapping was dependent on the generation of anonymous genetic markers and their anchoring on specific locations in the genome. This task, first achieved with restriction fragment length polymorphisms and then with other markers, such as microsatellites or sequence tag sites, enabled the introduction of whole-genome linkage analysis and positional cloning, which proved extremely useful in the identification of genetic mutations that cause monogenic disease. The linkage approach, which depends on the cosegregation of a causal mutation with the anonymous marker along the lines of inheritance in pedigrees composed of affected and unaffected members, is particularly useful for traits where disease-causing alleles are highly penetrant: that is, the presence of the genetic variant virtually always co-occurs with disease, and its absence co-occurs with absence of the disease. As such, in the diabetes field, linkage analysis facilitated the discovery of the genes that underlie the various types of monogenic diabetes, such as maturity-onset diabetes of the young (MODY) (12,16) or neonatal diabetes (17,18,19); these are described in detail in Chapter 7 Monogenic Forms of Diabetes.

In complex diseases, where the phenotype presumably arises as a combination of several genetic variants and their interaction with the environment, successful linkage analysis is considerably more difficult. Though it succeeded in demonstrating the strong influence of the human leukocyte antigen (HLA) region on type 1 diabetes (20,21), by and large, linkage analysis did not yield reproducible positive results for type 2 diabetes. This is because in type 2 diabetes there is not a single genetic locus that exerts a very strong effect in the general population or even in individual family pedigrees. Thus, the effect of genetic variation is probabilistic rather than deterministic; a substantial proportion of people with some risk variants may be disease-free, whereas others who carry protective alleles may instead have type 2 diabetes, due to a constellation of other factors. In such situations, the amount of information provided by meioses within families, on which the power of linkage analysis depends, is greatly reduced, and the number of families required can be inordinately large.

To demonstrate the effect of genetic variation on human phenotypes, an alternative approach was needed: association testing, which simply asks whether a specific allele is significantly overrepresented in diabetes cases compared to controls without diabetes, and which, with large sample size, has greater statistical power to detect a common variant of weak effect. Its major limitation—prior to 2005—was that only a handful of variants could be tested at a time, which required some prior biologic knowledge on the existence of such variants and the role of a given gene in diabetes pathophysiology. Although multiple genetic associations were described before 2005, only two of these stood the test of time, both at variants that change the amino acid sequence in genes that encode antihyperglycemic drug targets: the p.Pro12Ala polymorphism in the peroxisome proliferator-activated receptor gamma 2 (encoded by PPARG) (22) and the p.Glu23Lys polymorphism in the islet ATP-dependent potassium channel Kir6.2 (encoded by KCNJ11) (22,23). A third locus, a noncoding variant in the transcription factor 7-like 2 gene (TCF7L2), was discovered by large-scale association testing in areas of suggestive linkage (24). The common intronic rs7903146 polymorphism had the strongest statistical association (though with a modest odds ratio ~1.4) and the most widespread effect on type 2 diabetes risk (Figure 14.1) (25,26), albeit with an interesting exception in some Native American populations (27).

The panorama changed dramatically with the advent of genome-wide association studies (GWAS) (28). Several factors coalesced to enable the conduct of GWAS: the discovery of millions of single nucleotide polymorphisms (SNPs) and their deposition in public databases; the manufacturing of genotyping arrays that could simultaneously query hundreds of thousands of SNPs with great precision; the understanding of an underlying correlation structure between SNPs, driven by the finite number of recombination events in human history, which reduced the complexity of the variation to be interrogated; the recognition that the scientific imperative of reproducibility required the acceptance of strict statistical thresholds that accounted for the universe of possible hypotheses in the human genome; and the corollary of such awareness, that for these very small p-values to be achieved, very large sample sizes had to be assembled through international collaboration. Thus, for the first time, most of the common variants in the human genome (i.e., those with a minor allele frequency >5%) could be tested in one fell swoop.

FIGURE 14.1 Chronological Listing of Type 2 Diabetes-Associated Genes, Plotted by Year of Definitive Publication and Approximate Effect Size

Genes identified via the candidate gene approach are shown in green (*), genes identified via agnostic genome-wide association approaches are shown in blue (no symbol), genes identified by exome sequencing are shown in orange (†), and genes identified by whole-genome sequencing are shown in red (‡). TCF7L2 (shown at 2006) was discovered by dense fine-mapping under a linkage signal. TBC1D4 (shown last at 2014) was identified by exome sequencing of a locus found to be associated with a diabetes-related quantitative trait. Approximate allelic effect sizes were derived from the DIAGRAM (Diabetes Genetics Replication and Meta-analysis consortium) European ancestry meta-analysis (66) and the Asian ancestry meta-analysis (55) when possible. Gene names that are underlined denote identification in population isolates.

Bar graph showing the discovery of genes associated with type 2 diabetes increased from 3 before 2007 to several dozen in the G W A S era between 2007 and 2014

SOURCE: Adapted from Reference 26, copyright © 2017 Elsevier, reprinted with permission. Additional references listed within the legend.

Several independent GWAS (29,30,31,32,33) and the growing scientific exchange that led to successive meta-analyses of ever-increasing size (34,35) soon produced a plethora of robust associations, such that the landscape of type 2 diabetes-associated variants grew from three prior to the GWAS era to several dozen in just a few years (Figure 14.1, Table 14.1) (26,36,37). This list has been complemented by the implementation of similar approaches in the discovery of genetic determinants of quantitative glycemic traits (Table 14.2) (37,38,39,40,41,42,43,44,45), the extension of GWAS to non-European populations (46,47,48,49,50,51,52,53,54,55,56,57,58,59,60,61,62,63,64), trans-ethnic meta-analyses of many of these studies (56,65), and the deployment of custom-made arrays that allow for the rapid and efficient genotyping of top signals across thousands of additional samples (66,67).

A particularly illustrative example of a combination of these approaches has been furnished by Moltke et al. (68). On studying the population isolate of Greenland, they selected a custom-made array, the Metabochip (69), and focused on quantitative glycemic traits. They followed-up an original signal in TBC1D4 by sequencing the exons of this gene and identified a nonsense p.Arg684Ter variant of Inuit ancestry that is common in the Greenlandic population (frequency 17%) and is associated with 2-hour glucose and insulin levels. Stop codon homozygotes harbor a tenfold increased risk of type 2 diabetes compared to wildtype allele carriers. Definitive identification of the implicated protein allowed for functional studies: the stop codon induces lower protein levels of TBC1D4 in human skeletal muscle, causing reduced numbers of the glucose transporter GLUT4 and decreased insulin-stimulated glucose uptake, leading to postprandial hyperglycemia and impaired glucose tolerance.

TABLE 14.1 Genetic Loci Associated With Type 2 Diabetes at Genome-Wide Levels of Statistical Significance (p<5×10^−8^)

MARKER | CHR. | NEAREST GENE(S) | DISCOVERY COHORT(S) (REF.)
rs17106184 | 1 | FAF1 | 65
rs2296172 | 1 | MACF1 | 75
rs10923931 | 1 | NOTCH2 | 34
rs340874 | 1 | PROX1 * | 39
rs243021 | 2 | BCL11A | 35
rs3923113 | 2 | COBLL1/GRB14 | 51
rs780094 | 2 | GCKR * | 39
rs2943641 | 2 | IRS1 | 128
rs7560163 | 2 | RBM43/RND3 | 54
rs7593730 | 2 | RBMS1 | 129
rs7578597 | 2 | THADA | 34
rs6723108 | 2 | THEM163 | 58
rs4607103 | 3 | ADAMSTS9/PSMD6 | 34
rs11708067 | 3 | ADCY5 * | 39
rs4402960 | 3 | IGF2BP2 | 30,31,32
rs6808574 | 3 | LPP | 65
rs831571 | 3 | PSMD6 | 55
rs1801282 | 3 | PPARG | 22
rs16861329 | 3 | ST6GAL1 | 51
rs7612463 | 3 | UBE2E2 | 50
rs6815464 | 4 | MAEA | 55
rs6813195 | 4 | TMEM154 | 65
rs10010131 | 4 | WFS1 | 130
rs459193 | 5 | ANKRD55 | 66
rs702634 | 5 | ARL15 | 65
rs35658696 | 5 | PAM/PPIP5K2 | 77
rs4457053 | 5 | ZBED3 | 35
rs7754840 | 6 | CDKAL1 | 30,31,32,33
rs1535500 | 6 | KCNK16 | 55
rs3132524 | 6 | POU5F1/TCF19 | 65
rs9502570 | 6 | SSR1/RREB1 | 65
rs9470794 | 6 | ZFAND3 | 55
rs2191349 | 7 | DGKB/TMEM195 * | 39
rs6467136 | 7 | GCC1/PAX4 | 55
rs4607517 | 7 | GCK * | 39
rs864745 | 7 | JAZF1 | 34
rs972283 | 7 | KLF14 | 35
rs791595 | 7 | LEP | 62
rs516946 | 8 | ANK1 | 66
rs13266634 | 8 | SLC30A8 | 29
rs896854 | 8 | TP53INP1 | 35
rs1081161 | 9 | CDKN2A/B | 30,31,32
rs7041847 | 9 | GLIS3 | 55
rs11787792 | 9 | GPSM1 | 62
rs17584499 | 9 | PTPRD | 48
rs2796441 | 9 | TLE1 | 66
rs13292136 | 9 | TLE4 (formerly CHCHD9) | 35
rs12779790 | 10 | CDC123/CAMK1D | 34
rs10886471 | 10 | GRK5 | 57
rs1111875 | 10 | HHEX | 29
rs7903146 | 10 | TCF7L2 | 24
rs1802295 | 10 | VPS26A | 51
rs12571751 | 10 | ZMIZ1 | 66
rs1552224 | 11 | ARAP1 (formerly CENTD2) | 35
rs2334499 | 11 | DUSP8 | 116
rs5219/rs757110 | 11 | KCNJ11/ABCC8 | 23
rs2237892 | 11 | KCNQ1 | 46,47
rs10830963 | 11 | MTNR1B * | 38
rs2074356 | 12 | C12orf51 | 60
rs11065756 | 12 | CCDC63 | 60
rs11063069 | 12 | CCND2 | 66
rs1531343 | 12 | HMGA2 | 35
rs7957197 | 12 | HNF1A | 35
rs10842994 | 12 | KLHDC5 | 66
rs1727313 | 12 | MPHOSPH9 | 65
rs7961581 | 12 | TSPAN8/LGR5 | 34
rs9552911 | 13 | SGCG | 59
rs1359790 | 13 | SPRY2 | 49
rs61736969 | 13 | TBC1D4 * | 68
rs2007084 | 15 | AP3S2 | 51
rs4502156 | 15 | VPS13C/C2CD4A/B | 50
rs7178572 | 15 | HMG20A | 51
rs8042680 | 15 | PRC1 | 35
rs7403531 | 15 | RASGRP1 | 57
rs11634397 | 15 | ZFAND6 | 35
rs7202877 | 16 | BCAR1 | 66
rs9939609 | 16 | FTO | 131
rs4430796 | 17 | HNF1B | 132,133
rs312457 | 17 | SLC16A11/13 | 61,62
rs391300 | 17 | SRR | 48
rs12454712 | 18 | BCL2 | 56
rs8090011 | 18 | LAMA1 | 134
rs12970134 | 18 | MC4R | 66
rs10401969 | 19 | CILP2 | 66
rs8108269 | 19 | GIPR | 66
rs3786897 | 19 | PEPD | 55
rs4812829 | 20 | HNF4A | 51,55
rs5945326 | X | DUSP9 | 35

Loci are arranged alphabetically by chromosome number. One representative variant and one or two genes are provided for each locus. Loci are defined as association signals located within 500 kb of each other regardless of linkage disequilibrium. Chr, chromosome.

* Discovery of type 2 diabetes association followed detection in genome-wide association studies for quantitative glycemic traits (see Table 14.2).

SOURCE: Modified from Reference 37. References for individual discovery cohorts are listed within the table.

TABLE 14.2 Genetic Variants Associated With Quantitative Glycemic Traits at Genome-Wide Levels of Statistical Significance (p<5×10^−8^)

MARKER | CHR. | NEAREST GENE(S) | TRAIT | DISCOVERY COHORT(S) (REF.)
rs2820436 | 1 | LYPLAL1 | I | 43,67
rs340874 | 1 | PROX1 * | B | 39
rs9727115 | 1 | SNX7 | FP | 42
rs2779116 | 1 | SPTA1 | H | 41
rs6684514 | 1 | TMEM79 | H | 135
rs10195252 | 2 | COBLL1/GRB14 * | I | 43,67
rs1371614 | 2 | DPYSL5 | B | 43
rs560887; rs1402837 | 2 | G6PC2 | B; H | 39,41
rs780094; rs1260326 | 2 | GCKR * | B; I | 39,40
rs2972143 | 2 | IRS1 * | I | 43,67
rs733331 | 2 | PDK1/RAPGEF4 | B | 136
rs895636 | 2 | SIX2/SIX3 | B | 137
rs1530559 | 2 | YSK4 | I | 67
rs11708067; rs2877716 | 3 | ADCY5 * | B; I | 39,40
rs11715915 | 3 | AMT | B | 67
rs7651090 | 3 | IGF2BP2 * | B, I | 67
rs17036328 | 3 | PPARG * | I | 67
rs11920090 | 3 | SLC2A2 | B | 39
rs3822072 | 4 | FAM13A | I | 67
rs4691380 | 4 | PDGFC | I | 43,67
rs17046216 | 4 | SC4MOL | I | 135
rs9884482 | 4 | TET2 | I | 67
rs459193 | 5 | ANKRD55 * | I | 67
rs4865796 | 5 | ARL15 * | I | 67
rs1019503 | 5 | ERAP2 | I | 67
rs35658696 | 5 | PAM/PPIP5K2 * | I | 72
rs4869272; rs6235 | 5 | PCSK1 | B; FP | 43,67
rs7708285 | 5 | ZBED3 * | B | 67
rs9368222; rs7747752 | 6 | CDKAL1 * | B, H, I | 44,67,138
rs10305492 | 6 | GLP1R | G | 74
rs9399137 | 6 | HBS1L/MYB | H | 135
rs1800562 | 6 | HFE | H | 41
rs2745353 | 6 | RSPO3 | I | 67
rs17762454 | 6 | SSR1/RREB1 * | B | 67
rs6912327 | 6 | UHRF1BP1 | I | 43,67
rs2191349 | 7 | DGKB/TMEM195 * | B | 39
rs6947345 | 7 | EMID2 | B | 139
rs4607517,; rs730497 | 7 | GCK * | B, H, I | 39,41,44,67
rs6943153 | 7 | GRB10 | B | 44,67
rs1167800 | 7 | HIP1 | I | 67
rs6474359 | 8 | ANK1 * | B, H | 41,44
rs983309; rs11782386 | 8 | PPP1R3B | B; I | 43,67
rs11558471; rs13266634 | 8 | SLC30A8 * | B; FP | 39,42
rs651007 | 9 | ABO | B | 72,73
rs10811661 | 9 | CDKN2A/B * | B | 67
rs306549 | 9 | DDX31 | FP | 42
rs3829109 | 9 | DNLZ/GPSM1 * | B | 67
rs7034200 | 9 | GLIS3 * | B | 39
rs16913693 | 9 | IKBKAP | B | 67
rs3824420 | 9 | KANK1 | FP | 72,136
rs10885122 | 10 | ADRA2A | B | 39
rs7923866 | 10 | HHEX * | B | 44
rs7072268 | 10 | HKI | H | 41
rs10829854 | 10 | TCERG1L | I | 140
rs7903146 | 10 | TCF7L2 * | B, FP, I | 39,40,42,67
rs11603334 | 11 | ARAP1 * | B, FP | 42,43,67
rs11605924 | 11 | CRY2 | B | 39
rs174550 | 11 | FADS1 | B | 39
rs174570 | 11 | FADS2 | H | 135
rs7944584 | 11 | MADD | B, FP | 39,42
rs10830963 | 11 | MTNR1B * | B, H | 38,41,44,141,142
rs1483121 | 11 | OR4S1 | B | 43
rs2074356 | 12 | C12orf51 * | B | 143
rs2657879 | 12 | GLS2 | B | 67
rs2650000 | 12 | HNF1A * | B | 72
rs35767 | 12 | IGF1 | I | 39
rs122229654 | 12 | MYL2 | I | 143
rs11066453 | 12 | OAS1 | I | 143
rs10747083 | 12 | P2RX2 | B | 67
rs17331697 | 12 | RMST | B | 139
rs150781447 | 12 | TBCD130 | FP | 72
rs7998202 | 13 | ATP11A | H | 41
rs576674 | 13 | KL | B | 67
rs11619319 | 13 | PDX1 | B | 43,67,77
rs61736969 | 13 | TBC1D4 * | B, I | 68
rs3783347 | 14 | WARS | B | 67
rs11071657 | 15 | VPS13C/C2CD4A/B * | B, FP, I | 39,40,42,44
rs2018860 | 15 | IGF1R | B | 136
rs1549318 | 15 | LARP6 | FP | 42
rs9933309 | 16 | CYBA | H | 135
rs1421085 | 16 | FTO * | I | 67
rs1046896 | 17 | FN3K | H | 41
rs4790333 | 17 | SGSM2 | FP | 42
rs10423928 | 19 | GIPR * | B, I | 40,44,67
rs11667918 | 19 | MYO9B | H | 135
rs731839 | 19 | PEPD * | I | 67
rs6113722 | 20 | FOXA2 | B | 43,67
rs6072275 | 20 | TOP1 | B | 67
rs855791 | 22 | TMPRSS6 | H | 41

Loci are arranged alphabetically by chromosome number. One representative variant and one or two genes are provided for each locus for each glycemic trait. Loci are defined as association signals located within 500 kb of each other regardless of linkage disequilibrium. B, beta cell (fasting glucose, HOMA-B, corrected insulin response, disposition index, insulinogenic index, or these traits adjusted for BMI); BMI, body mass index; Chr, chromosome; FP, fasting proinsulin; H, hemoglobin A1c; HOMA-B and HOMA-IR, beta cell function and insulin resistance by homeostasis model assessment, respectively; I, insulin resistance (fasting insulin, 1-hour glucose, 2-hour glucose, HOMA-IR, or these traits adjusted for BMI).

* Locus is also associated with type 2 diabetes.

SOURCE: Modified from Reference 37. References for individual discovery cohorts are listed within the table.

However, many of these GWAS only captured common variants, because imputation of ungenotyped variants depended on available reference panels from resources such as the HapMap (70). The introduction of massive parallel sequencing techniques and the concomitant dramatic drop in cost allowed for efficient, high-fidelity sequencing of thousands of samples. This enabled three major developments: first, denser reference panels could be developed for more accurate imputation of less common variants (71); second, targeted genotyping arrays that included less common but likely functional variation (e.g., coding variants) could be designed; and third, the allelic spectrum captured in case-control or quantitative trait studies could be expanded into less common frequencies, so that population genetics by which a rare variant may rise to prominence in a specific ethnic group could be exploited.

Arrays containing exome content deployed in large populations have identified coding variants in established or novel genes associated with type 2 diabetes or related quantitative traits (72,73,74). By detecting a robust association signal in the coding region of a specific gene (e.g., SGSM2 and proinsulin levels) (72), these studies serve to advance the candidacy of said gene as the causal locus, from within the various possibilities under a noncoding GWAS association peak (42). Beyond genotyping, sequencing of whole exomes in Europeans (75) and Mexicans (76) has also yielded novel associations, and the extensive genetic and pedigree data available in the Icelandic population have allowed whole-genome sequences in 2,630 Icelanders to be extrapolated to a sample size of 11,114 type 2 diabetes cases and 267,140 controls for additional discovery (77). Finally, whole-genome sequencing in 2,657 European individuals with and without diabetes and whole-exome sequencing in 12,940 individuals from five ancestry groups have begun to shed light on the genetic architecture of type 2 diabetes in a more systematic fashion, in terms of plausible effect sizes, observed allelic frequencies, and the potential number of causal variants (78). All in all, these studies support a model in which type 2 diabetes is caused by hundreds or thousands of loci of modest effects, with no major role for low-frequency variants of strong effects in disease predisposition.

## Insights Gained

The tremendous success of GWAS and their follow-up for type 2 diabetes and other human phenotypes have resulted in a number of insights into the genetic architecture of type 2 diabetes.

Although the functional variants at most type 2 diabetes-associated loci are not yet known, most associated loci are located near genes that were previously unsuspected to play a role in type 2 diabetes pathophysiology. This observation highlights the complexity of the disease phenotype and the power of agnostic approaches in unearthing new knowledge. Conversely, it brings to the forefront the constraints imposed by prior knowledge on scientific inquiry and points to the inadequacy of prior candidate gene selection efforts, as most “logical” candidate genes did not yield significant associations. This observation does not necessarily minimize the role of such biologic candidates on glucose homeostasis; rather, it may indicate natural selection’s little tolerance for functional variation in those key genes.

Noncoding variation can affect human phenotypes. The SNPs with the strongest associations are often found in introns, regulatory regions, or intergenic segments, i.e., they do not change the amino acid sequence of the encoded proteins. Furthermore, for the most part, no obvious missense SNP has been identified in coding regions for which the associated SNP was a proxy and, thus, might have explained the association signal. The human genome is rife with regulatory sequences that influence the timing, location, and level of expression of genes (79), and these are thought to have a substantial impact on human biology.

Most genetic determinants of type 2 diabetes have modest effects. No common variant that is widely shared across populations has been found to have a stronger effect than the rs7903146 SNP in TCF7L2. The handful of variants with stronger effects (e.g., TBC1D4 p.Arg684Ter in Greenland, odds ratio ~10 (68), or HNF1A p.Glu508Lys in Mexico, odds ratio ~5 (76)) are either rare or unique to specific populations. Moreover, pioneering whole-exome and whole-genome sequencing experiments in thousands of samples across multiple ethnic groups have failed to unveil a plethora of rare variant associations, and they have not provided support for the hypothesis that common variant association signals are undergirded by rare variants of strong effects (78,80). Thus, the genetic architecture of type 2 diabetes appears to involve hundreds of variants with modest effects (66,78,81). While rare variants might be found that have stronger effects in specific families or population groups, they are most likely to be private, as shared rare variants of strong effects should have been found by linkage. A corollary of this observation is that any single variant is unlikely to have significant predictive power in the individual, and even when many variants are combined into a genotype risk score (GRS), predictive power is poor. Together, the approximately 100 loci associated with type 2 diabetes thus far explain ~10%–15% of the familial aggregation of the disease, or 5.7% of the variance in type 2 diabetes susceptibility (66).

The majority of genetic variants that influence type 2 diabetes risk affect beta cell function (Figure 14.2) (35,82,83). Human studies have shown that most of the identified variants (whether causal or tagging a causal variant) are associated with impaired beta cell function, directly or indirectly (83). Insulin secretion appears to be more heritable than insulin resistance (39,84), confirming the pathogenic hypothesis put forth by early geneticists, by which a mostly environmental insult causing insulin resistance is overlaid on a mostly genetic predisposition to beta cell dysfunction.

The genetic architecture of beta cell function and insulin action seem to differ (Figure 14.3) (39). As mentioned, measures of estimating beta cell function in humans are more amenable to genetic approaches (i.e., they have a higher likelihood of yielding significant findings) than measures of insulin sensitivity (39,84). Incorporating adiposity as a modulator of insulin resistance (43) or focusing genetic investigation on more sophisticated and refined measures of insulin sensitivity (45) has yielded additional loci; nevertheless, the majority of type 2 diabetes-associated loci for which a physiologic mechanism has been determined seem to influence beta cell function (35,83). Insulin resistance might be influenced by fewer loci, less frequent variants or those with more modest effects, or a stronger environmental component.

FIGURE 14.2 Two-Dimensional Plot of Type 2 Diabetes-Associated Loci Placed in Relationship to Beta Cell Function and Insulin Resistance

Fasting measures of beta cell function (HOMA-B, X axis) and insulin resistance (HOMA-IR, Y axis) were obtained by homeostasis model assessment. The majority of loci are associated with impaired beta cell function, though some do clearly impact insulin resistance. Colors and shapes denote the significance level of the association to HOMA-B. The two KCNQ1 associations are distinguished by the notation KCNQ1 for rs163184 and KCNQ1* for rs231362.

Scatter plot showing that genetic variants linked to type 2 diabetes risk more often affect beta cell function than insulin resistance

SOURCE: Reference 35, copyright © 2010 Nature Publishing Group, reprinted with permission

FIGURE 14.3 Quantile-Quantile Plots for Genome-Wide Association Studies of Beta Cell Function and Insulin Resistance

Homeostasis model assessments of beta cell function (HOMA-B) and insulin resistance (HOMA-IR) were generated for the Meta-analyses of Glucose and Insulin-related Traits Consortium (MAGIC) meta-analysis of fasting glycemic traits. The quantile-quantile plot illustrates the observed p-values in the full distribution versus those that would be expected under the null hypothesis of no association. The HOMA-B p-values have a larger deviation from expected compared to HOMA-IR, indicating that genetic associations with HOMA-B are more likely to be detected than those with HOMA-IR. The fasting insulin distribution (not shown) parallels that of HOMA-IR, suggesting that the plot illustrates the true genetic architecture of the trait and is not affected by the use of a mathematical formula to calculate HOMA-IR. Because the same number of samples and types of insulin assays were used to estimate HOMA-B and HOMA-IR, sample size and assay heterogeneity cannot be invoked to explain the observed difference.

Quantile-quantile graph showing that measures of beta cell function have a higher likelihood of yielding significant findings than measures of insulin sensitivity

SOURCE: Reference 39, copyright © 2010 Nature Publishing Group, adapted with permission

The genes that elevate fasting glucose in normal individuals are not necessarily the same genes that cause type 2 diabetes. While a simple model would predict that any locus that raises fasting glucose should raise risk of type 2 diabetes, the exploration of genetic determinants of glucose homeostasis in nondiabetic individuals has yielded a number of variants that do both (i.e., raise fasting glucose and increase type 2 diabetes risk), but also a non-trivial number that raise fasting glucose without appreciably increasing risk of type 2 diabetes. This observation has led physiologists to consider not just the magnitude of the glucose increase, but the manner in which this happens, as relevant to the emergence of disease (39). A simple elevation of the glucose set point, for example, may not necessarily lead to hyperglycemia in the diabetes range, if beta cell function is otherwise intact; however, an alteration that leads to progressive beta cell deterioration would cause diabetes in the future.

Genetic studies support prior epidemiologic observations. A GWAS for fasting glucose yielded significant associations near two circadian genes (MTNR1B and CRY2) (39). A growing literature implicates circadian dysregulation, through epidemiologic reports (85), animal studies (86,87), and human perturbation experiments (88), in metabolically deleterious phenotypes. Thus, a GWAS for glycemia provides a potential genetic link between the two systems. Similarly, a SNP in ADCY5 has been associated with fasting glucose, type 2 diabetes, and low birth weight, once again corroborating the known relationship between being born small for gestational age and future risk of obesity and diabetes (89). In addition, SNPs in FTO and MC4R contribute to obesity, insulin resistance, and type 2 diabetes, thus connecting various components of the metabolic syndrome (67,90).

FIGURE 14.4 Loci Initially Identified in Populations of European Descent Appear to Have Similar Effects in Other Racial/Ethnic Groups

Genetic risk scores constructed from variants associated with fasting glucose by the Meta-analyses of Glucose and Insulin-related Traits Consortium (MAGIC) investigators (39) or the Diabetes Genetics Replication and Meta-analysis (DIAGRAM) consortium (35) in populations of European descent also predict, in aggregate, rising glucose or type 2 diabetes in other racial/ethnic groups. (A) Data obtained for fasting glucose from the National Health and Nutrition Examination Surveys 1991–1994 (92). (B) Data obtained for type 2 diabetes using the IBC (ITMAT-Broad-CARe) chip (56). AfAm, African American; As, Asian; His, Hispanic; MA, Mexican American; NHB, non-Hispanic black; NHW, non-Hispanic white.

Graph showing genetic risk scores developed in people of European descent are associated with fasting glucose and type 2 diabetes when applied to people of non-European descent

SOURCE: References are listed within the figure legend.

Most common risk variants are shared across ethnic groups. Although GWAS of comparable size and power have not yet been performed in non-European populations, when investigators have tried to ascertain whether common variants that influence these traits in people of European descent also do so in individuals of other continental ancestries, by and large, they have found similar effects; though, some loci do show heterogeneity. Once allele frequency differences and altered haplotype structures are taken into account, analogous patterns of association emerge in African American, Hispanic, Asian, or Native American populations (Figure 14.4) (56,91,92,93).

Genetic information does not add much beyond clinical variables for type 2 diabetes prediction. Commonly ascertained clinical variables are fairly precise at capturing future risk of type 2 diabetes (10); thus, adding the set of common variants known to date (which only explains a minor fraction of the genetic predisposition to type 2 diabetes) does not seem to improve predictive accuracy at the individual level or the ability to discriminate between risk strata in a clinically meaningful way (94,95,96). Prediction is slightly improved in younger individuals, in whom clinical risk factors are not yet fully manifest.

An intensive lifestyle intervention is effective in people with the highest burden of known risk alleles. The Diabetes Prevention Program showed that an intensive lifestyle intervention, consisting of dietary and physical activity components, is effective even in the quartile of participants who carry the highest load of known risk variants (Figure 14.5) (97).

Genetic variation may affect drug response. Genetic information may eventually be used to guide medication choices in type 2 diabetes. Though this is the standard of care for monogenic diabetes with examples in both MODY and neonatal diabetes (98,99), the potential of genetically guided therapy is yet to be realized in common type 2 diabetes. A polymorphism in a metformin transporter may affect glycemic response to metformin (100,101,102), and a GWAS for metformin response in people with type 2 diabetes has identified a polymorphism near the ATM gene that influences metformin response in several independent cohorts (103,104), although it does not seem to exert the same effect for diabetes prevention in people with prediabetes (105). Some sulfonylureas are metabolized by the cytochrome P450 enzyme CYP2C9, and patients with loss-of-function variants in this gene are at increased risk of sulfonylurea-related hypoglycemia (106). These early pharmacogenomic lessons suggest that genes relevant to drug response may be the same as those that increase risk for type 2 diabetes, or they may be different.

FIGURE 14.5 An Intensive Lifestyle Intervention, as Deployed in the Diabetes Prevention Program, is Effective Regardless of Genetic Risk Score for Type 2 Diabetes

Diabetes Prevention Program participants were stratified by quartile of genetic risk constructed by adding risk alleles from 34 known type 2 diabetes-associated variants. Whereas the GRS predicts diabetes incidence in the placebo arm, it does not do so in the lifestyle arm; indeed, the intervention is highly effective in reducing diabetes incidence even in the quartile with the highest genetic risk. GRS, genetic risk score; ILS, intensive lifestyle; MET, metformin; PBO, placebo.

Bar graph showing that an intensive lifestyle intervention reduced the incidence rate of diabetes consistently among people in each quartile of genetic risk score

SOURCE: Reference 97, copyright © 2011 American Diabetes Association, reprinted with permission from the American Diabetes Association

## Limitations of Current Approaches (and Their Solutions)

Despite the overwhelming success of GWAS strategies in advancing knowledge of the genetic determinants of type 2 diabetes, a number of limitations must be recognized. These limitations have been identified by the research community and are being addressed to complement gaps in understanding.

GWAS were initially undertaken only in populations of European descent. A large swath of genetic variation is unique to other populations, especially those of African descent, due to the bottleneck introduced when a limited subset of human ancestors migrated out of Africa. In addition, genetic variants have been identified that, though present in Europeans, are much more common in other populations, thereby acquiring greater statistical power to detect modest effects. As described above, GWAS efforts in East Asian (46,47,48,49,50,55,57,60,62), South Asian (51,58,59), African American (54,63), Hispanic (52,53,61), and Native American (64) cohorts have already yielded novel genome-wide significant findings, many of which are also seen in Europeans. As larger consortia and trans-ethnic meta-analyses are undertaken, more novel findings are expected to come to light.

GWAS of large cohorts suffer from relatively crude phenotyping. Because sample size is paramount to achieve adequate statistical power, GWAS are typically carried out in very large population cohorts where only limited phenotyping is feasible. The estimates of beta cell function or insulin sensitivity derived from simple measures, such as fasting glucose or insulin (107) (as opposed to those obtained from more labor-intensive and costly dynamic testing), are relatively imprecise. However, some of the participating cohorts do have more sophisticated phenotyping: while the participants have contributed their simple traits to the meta-analytic efforts, the investigators are also able to form subconsortia where additional physiologic inquiry can be carried out. This type of analysis has been performed for proinsulin levels adjusted for fasting insulin (42), various dynamic measures of insulin secretion (44), and insulin sensitivity derived from clamp studies (45), and it is underway for insulin sensitivity derived from oral glucose tolerance tests (108) and insulin clearance (109,110).

GWAS only capture common variants. Due to the composition of genotyping arrays and statistical issues around rare observations, most GWAS to date have concentrated solely on common variation (i.e., minor allele frequency >5%). The introduction of next-generation DNA sequencing technologies has allowed for a downward expansion in the characterization of shared uncommon variation, as sequencing >1,000 individuals from multiple ethnic groups in the 1000 Genomes Project (71) has produced a catalog of uncommon variants that can be captured by their correlation to previously known common variants. Imputation to these 1000 Genomes panels is expanding the subset of testable variants in extant meta-analyses. The pioneering whole-exome (75,76) and whole-genome (77) sequencing studies described above are beginning to yield fruit, particularly when expanded to larger multi-ethnic samples (78). Nevertheless, under a model that the genetic architecture of type 2 diabetes is composed of several thousand variants of modest effects (66,81), even sequencing experiments require sample sizes of upwards of 25,000 cases to detect true associations, as either effect size or allele frequency is limiting (111).

Most analyses have not taken into account interactions with the environment. Type 2 diabetes results from complex interactions among multiple genetic and environmental factors, and the rapid rise of its prevalence cannot be attributed to genetics. Because most GWAS are designed to detect loci that have main effects on type 2 diabetes risk, regardless of the environmental context, many variants whose impact varies according to an environmental parameter might be missed. This is due in part to the imprecision inherent to environmental measures and the noise introduced by a single cross-sectional environmental exposure; in contrast, genotyping methods are extremely accurate, and the genetic exposure is uniform across an individual’s lifetime. Nevertheless, analytical methods are being developed that allow for the joint inquiry of main gene effects and gene × environment interactions (112), and these methods have already been deployed to identify loci for insulin sensitivity (43) and for the regulation of body mass index (113).

Analyses of predictive properties have only included the SNPs meeting genome-wide significance. Analytical methods have been developed that utilize information from the entire genome (114,115), and these methods may provide better predictive properties than models that use only the established SNPs that have met genome-wide significance. The clinical utility of such approaches remains to be determined.

Most analyses are simple additive tests for association and do not explore more complex modes of inheritance. There are good statistical reasons to primarily base GWAS experiments on the additive genetic model, in which the presence of two copies of the risk allele in an individual essentially doubles the risk associated with a single allele. This may not always be the case: in the two extreme examples, under a dominant model, two copies of the risk allele will not add any further risk to that conferred by a single copy, and under a recessive model, the risk will not be made manifest unless both copies are present. While the majority of type 2 diabetes-associated SNPs have been found to exert their action via an additive model, this is expected as their discovery took place precisely under such a model. A comprehensive examination of alternative modes of inheritance is needed in the existing GWAS datasets, which now are reaching adequate sizes to compensate for the smaller number of homozygous minor allele carriers and for the penalty incurred by additional statistical testing. Similarly, tests of gene × gene interactions (epistasis) and accounting for divergent effects depending on parental line of inheritance, where that information is available (116), are likely to yield additional loci.

GWAS only identify correlated SNPs but do not yield the causal variant. Because GWAS leverage the correlative structure of the human genome to identify associations, they simply point to regions of the genome in which certain alleles are overrepresented in cases versus controls. Identifying which of the SNPs present in that segment is the actual molecular cause of the disease phenotype requires fine-mapping and functional studies. Fine-mapping can be performed by sequencing and saturation genotyping of all variants in the associated segment, retesting them and their haplotypes (linear arrangements of SNPs in a chromosome) for association with the phenotype. While custom-made arrays have been designed to achieve this task in type 2 diabetes and related metabolic traits (69), the conditional statistical testing that is required to distinguish the strength of the association of one variant from another’s is laborious and requires inordinate sample sizes. Oftentimes, functional experiments are needed to establish which of the equally associated variants is pathogenic; these efforts have succeeded in some cases, for instance, in identifying the p.Ser1369Ala polymorphism in the sulfonylurea receptor gene ABCC8 as the likely culprit for gliclazide response, rather than its tightly linked nearby polymorphism p.Glu23Lys in KCNJ11 (117).

The road from association to function is arduous. As intimated in the previous point, a genetic association does not necessarily yield insights into molecular function. While this may be relatively easier to establish for coding missense variants that change amino acid sequence (because appropriate protein-based experiments can be designed), only a handful of type 2 diabetes associations fulfill this description (KCNJ11 p.Glu23Lys/ABCC8 p.Ser1369Ala, SLC30A8 p.Arg235Trp, and GCKR p.Pro446Leu). For many other variants that fall in regulatory regions, a different sort of investigation must be designed (118). The publication of a comprehensive catalog of functional regulatory elements in the human genome and availability of public tissue expression data linked to genotype data should facilitate this task enormously (79,119). The ability to perform genome editing (e.g., with CRISPR/CAS9) in informative experimental systems, such as induced pluripotent stem cells, should also greatly expand the ability to investigate function.

A pioneering illustration of how such an effort can yield fruits was achieved for TCF7L2: fine-mapping had established rs7903146 as the likely culprit SNP, and physiologic studies had placed its pathogenic activity squarely in the beta cell (120,121); an intelligent integration of these data with areas of open chromatin in beta cells, combined with expression experiments, led to the determination that rs7903146 affects an enhancer element that regulates TCF7L2 expression (122). In another example, KLF14 had been associated with type 2 diabetes, but the risk allele appeared to cause insulin resistance (35); by combining the GWAS finding with expression datasets in adipose tissue, the associated SNP was discovered to influence expression of KLF14, which itself is a master regulator of adipose gene expression and thereby responsible for multiple metabolic phenotypes (123). Analogous experiments have clarified the role of SNPs around the glucose-6-phosphatase catalytic subunit 2 gene (G6PC2) (124). A fuller description of successful association-to-function efforts in type 2 diabetes is available elsewhere (125).

## The Future of Research on the Genetics of Type 2 Diabetes

Given the rapid progress achieved in genetic discovery in type 2 diabetes and the multipronged approach deployed to overcome experimental limitations, there is great hope that the pace will be maintained and a substantial part of the genetic architecture of type 2 diabetes will be elucidated in the coming years. If this vision is realized, a number of conceptual advances can be expected.

The nosology of disease will be refined. Type 2 diabetes, diagnosed solely on the basis of the final common pathway of hyperglycemia, is likely a heterogeneous syndrome that can be caused by a variety of processes (126). Genetic etiologies have already helped classify the various forms of MODY and neonatal diabetes, and an analogous exercise could take place in type 2 diabetes. The categorization of the disease into subtypes based on genetic determinants of physiology, prognosis, or predisposition to complications should help stratify the patient population into groups for which therapeutic or surveillance decisions might be better tailored.

Novel pathways will be identified. Unsuspected biology is already being uncovered via genetic discovery. With a greater number of genetic loci at hand, pathways or systems (e.g., cell proliferation) can be identified, some of which may be amenable to the development of new therapeutics.

Genetic discovery may identify drug targets. As mentioned above, among the initial type 2 diabetes genetic associations were coding variants for PPARG, the gene that encodes the target of thiazolidinediones (22), and KCNJ11/ABCC8, the genes that encode the targets for sulfonylureas (23,127). More recent studies have identified the target for glucagon-like peptide 1 receptor agonists as another type 2 diabetes-associated gene (73,74). This proof of principle for established type 2 diabetes drug targets indicates that among the many type 2 diabetes-associated loci, there might be other genes for which a suitable drug might be found or developed. Aggregating all of the genetic data in humans and model systems, as well as ancillary associations that might point to off-target effects, will be essential if the genomic revolution is to catalyze new drug discovery.

Stratification of patients may allow for better targeting of public health or clinical trial interventions. Some preventive or therapeutic measures may be too expensive to deploy in the population at large, or they may be futile in specific subgroups. Genetic characterization may help identify the groups of people more likely to benefit from particular public health strategies. Similarly, the efficiency of clinical trials may be enhanced by enrolling participants who are more likely to reach the desired endpoints or benefit from the agents being tested.

Genetics may facilitate the implementation of precision or personalized medicine. Though it is not yet clear that genetic information will be powerful enough to apply therapeutic decisions at the individual level, it may help do so for specific subgroups. For example, genetic approaches may unveil who is more likely to develop a particular diabetic complication. For such an approach to be feasible, researchers envision that in the not too distant future, any individual who joins a public or private health care system would be genotyped or sequenced for the full list of actionable genetic variants (e.g., those that modify risk of common diseases or response to available medications), such that his/her information is available in the electronic medical record. When the time comes to make specific screening or therapeutic decisions, genetic information filtered through appropriate decision support tools would automatically guide the practitioner into the course of action most appropriate to the person and situation at hand.

## Conclusion

In sum, the genetics of type 2 diabetes is in a steep discovery curve. Progress has been uneven, however, with most efforts focused on common variants and populations of European descent. The rapid and continuing progress in genotyping and sequencing technologies, with a concomitant improvement in affordability, the growing understanding of the human genome, and the ongoing development of analytical tools and methods present an optimistic perspective on the future. Whether this newfound knowledge will translate into improved patient care depends on the ability to design and execute genetically based and outcomes-driven clinical trials.

## List of Abbreviations

GWAS: genome-wide association study
MODY: maturity-onset diabetes of the young
PPARG: peroxisome proliferator-activated receptor gamma
SNP: single nucleotide polymorphism
TCF7L2: transcription factor 7-like 2

## References

1 Barnett AH, Eff C, Leslie RD, Pyke DA: Diabetes in identical twins. A study of 200 pairs. Diabetologia 20:87–93, 1981 7193616
2 Newman B, Selby JV, King MC, Slemenda C, Fabsitz R, Friedman GD: Concordance for type 2 (non-insulin-dependent) diabetes mellitus in male twins. Diabetologia 30:763–768, 1987 3428496
3 Kaprio J, Tuomilehto J, Koskenvuo M, Romanov K, Reunanen A, Eriksson J, Stengard J, Kesaniemi YA: Concordance for type 1 (insulin-dependent) and type 2 (non-insulin-dependent) diabetes mellitus in a population-based cohort of twins in Finland. Diabetologia 35:1060–1067, 1992 1473616
4 Meigs JB, Muller DC, Nathan DM, Blake DR, Andres R; Baltimore Longitudinal Study of Aging: The natural history of progression from normal glucose tolerance to type 2 diabetes in the Baltimore Longitudinal Study of Aging. Diabetes 52:1475–1484, 2003 12765960
5 Poulsen P, Kyvik KO, Vaag A, Beck-Nielsen H: Heritability of type II (non-insulin-dependent) diabetes mellitus and abnormal glucose tolerance—a population-based twin study. Diabetologia 42:139–145, 1999 10064092
6 Bennett PH, Burch TA, Miller M: Diabetes mellitus in American (Pima) Indians. Lancet 2:125–128, 1971 4104461
7 Ferrannini E, Nannipieri M, Williams K, Gonzales C, Haffner SM, Stern MP: Mode of onset of type 2 diabetes from normal or impaired glucose tolerance. Diabetes 53:160–165, 2004 14693710
8 Knowler WC, Pettitt DJ, Saad MF, Bennett PH: Diabetes mellitus in the Pima Indians: incidence, risk factors and pathogenesis. Diabetes Metab Rev 6:1–27, 1990 2192853
9 Lyssenko V, Almgren P, Anevski D, Perfekt R, Lahti K, Nissen M, Isomaa B, Forsen B, Homstrom N, Saloranta C, Taskinen MR, Groop L, Tuomi T; Botnia Study Group: Predictors of and longitudinal changes in insulin sensitivity and secretion preceding onset of type 2 diabetes. Diabetes 54:166–174, 2005 15616025
10 Wilson PW, Meigs JB, Sullivan L, Fox CS, Nathan DM, D’Agostino RB, Sr.: Prediction of incident diabetes mellitus in middle-aged adults: the Framingham Offspring Study. Arch Intern Med 167:1068–1074, 2007 17533210
11 Velho G, Froguel P: Genetic, metabolic and clinical characteristics of maturity onset diabetes of the young. Eur J Endocrinol 138:233–239, 1998 9539292
12 Fajans SS, Bell GI, Polonsky KS: Molecular mechanisms and clinical pathophysiology of maturity-onset diabetes of the young. N Engl J Med 345:971–980, 2001 11575290
13 Almgren P, Lehtovirta M, Isomaa B, Sarelin L, Taskinen MR, Lyssenko V, Tuomi T, Groop L; Botnia Study Group: Heritability and familiality of type 2 diabetes and related quantitative traits in the Botnia Study. Diabetologia 54:2811–2819, 2011 21826484
14 Willemsen G, Ward KJ, Bell CG, Christensen K, Bowden J, Dalgard C, Harris JR, Kaprio J, Lyle R, Magnusson PK, Mather KA, Ordonana JR, Perez-Riquelme F, Pedersen NL, Pietilainen KH, Sachdev PS, Boomsma DI, Spector T: The concordance and heritability of type 2 diabetes in 34,166 twin pairs from international twin registers: the Discordant Twin (DISCOTWIN) Consortium. Twin Res Hum Genet 18:762–771, 2015 26678054
15 Carter JS, Pugh JA, Monterrosa A: Non-insulin-dependent diabetes mellitus in minorities in the United States. Ann Intern Med 125:221–232, 1996 8686981
16 Vaxillaire M, Froguel P: Genetic basis of maturity-onset diabetes of the young. Endocrinol Metab Clin North Am 35:371–384, 2006 16632099
17 Gloyn AL, Pearson ER, Antcliff JF, Proks P, Bruining GJ, Slingerland AS, Howard N, Srinivasan S, Silva JM, Molnes J, Edghill EL, Frayling TM, Temple IK, Mackay D, Shield JP, Sumnik Z, van Rhijn A, Wales JK, Clark P, Gorman S, Aisenberg J, Ellard S, Njolstad PR, Ashcroft FM, Hattersley AT: Activating mutations in the gene encoding the ATP-sensitive potassium-channel subunit Kir6.2 and permanent neonatal diabetes. N Engl J Med 350:1838–1849, 2004 15115830
18 Babenko AP, Polak M, Cave H, Busiah K, Czernichow P, Scharfmann R, Bryan J, Aguilar-Bryan L, Vaxillaire M, Froguel P: Activating mutations in the ABCC8 gene in neonatal diabetes mellitus. N Engl J Med 355:456–466, 2006 16885549
19 Sagen JV, Raeder H, Hathout E, Shehadeh N, Gudmundsson K, Baevre H, Abuelo D, Phornphutkul C, Molnes J, Bell GI, Gloyn AL, Hattersley AT, Molven A, Sovik O, Njolstad PR: Permanent neonatal diabetes due to mutations in KCNJ11 encoding Kir6.2: patient characteristics and initial response to sulfonylurea therapy. Diabetes 53:2713–2718, 2004 15448106
20 Davies JL, Kawaguchi Y, Bennett ST, Copeman JB, Cordell HJ, Pritchard LE, Reed PW, Gough SC, Jenkins SC, Palmer SM, Balfour KM, Rowe BR, Farrall M, Barnett AH, Bain SC, Todd JA: A genome-wide search for human type 1 diabetes susceptibility genes. Nature 371:130–136, 1994 8072542
21 Hashimoto L, Habita C, Beressi JP, Delepine M, Besse C, Cambon-Thomsen A, Deschamps I, Rotter JI, Djoulah S, James MR, Froguel P, Weissenbach J, Lathrop GM, Julier C: Genetic mapping of a susceptibility locus for insulin-dependent diabetes mellitus on chromosome 11q. Nature 371:161–164, 1994 8072544
22 Altshuler D, Hirschhorn JN, Klannemark M, Lindgren CM, Vohl MC, Nemesh J, Lane CR, Schaffner SF, Bolk S, Brewer C, Tuomi T, Gaudet D, Hudson TJ, Daly M, Groop L, Lander ES: The common PPARg Pro12Ala polymorphism is associated with decreased risk of type 2 diabetes. Nat Genet 26:76–80, 2000 10973253
23 Gloyn AL, Weedon MN, Owen KR, Turner MJ, Knight BA, Hitman G, Walker M, Levy JC, Sampson M, Halford S, McCarthy MI, Hattersley AT, Frayling TM: Large-scale association studies of variants in genes encoding the pancreatic beta-cell KATP channel subunits Kir6.2 (KCNJ11) and SUR1 (ABCC8) confirm that the KCNJ11 E23K variant is associated with type 2 diabetes. Diabetes 52:568–572, 2003 12540637
24 Grant SF, Thorleifsson G, Reynisdottir I, Benediktsson R, Manolescu A, Sainz J, Helgason A, Stefansson H, Emilsson V, Helgadottir A, Styrkarsdottir U, Magnusson KP, Walters GB, Palsdottir E, Jonsdottir T, Gudmundsdottir T, Gylfason A, Saemundsdottir J, Wilensky RL, Reilly MP, Rader DJ, Bagger Y, Christiansen C, Gudnason V, Sigurdsson G, Thorsteinsdottir U, Gulcher JR, Kong A, Stefansson K: Variant of transcription factor 7-like 2 (TCF7L2) gene confers risk of type 2 diabetes. Nat Genet 38:320–323, 2006 16415884
25 Cauchi S, El Achhab Y, Choquet H, Dina C, Krempler F, Weitgasser R, Nejjari C, Patsch W, Chikri M, Meyre D, Froguel P: TCF7L2 is reproducibly associated with type 2 diabetes in various ethnic groups: a global meta-analysis. J Mol Med (Berl) 85:777–782, 2007 17476472
26 Udler MS, Florez JC: Diabetes genomics. In Genomic and Precision Medicine: Primary Care. Ginsburg GS, Willard HF, David SP, Eds. Amsterdam, Academic Press, 2017, in press
27 Guo T, Hanson RL, Traurig M, Muller YL, Ma L, Mack J, Kobes S, Knowler WC, Bogardus C, Baier LJ: TCF7L2 is not a major susceptibility gene for type 2 diabetes in Pima Indians: analysis of 3,501 individuals. Diabetes 56:3082–3088, 2007 17909099
28 McCarthy MI, Abecasis GR, Cardon LR, Goldstein DB, Little J, Ioannidis JP, Hirschhorn JN: Genome-wide association studies for complex traits: consensus, uncertainty and challenges. Nature Rev Genet 9:356–369, 2008 18398418
29 Sladek R, Rocheleau G, Rung J, Dina C, Shen L, Serre D, Boutin P, Vincent D, Belisle A, Hadjadj S, Balkau B, Heude B, Charpentier G, Hudson TJ, Montpetit A, Pshezhetsky AV, Prentki M, Posner BI, Balding DJ, Meyre D, Polychronakos C, Froguel P: A genome-wide association study identifies novel risk loci for type 2 diabetes. Nature 445:881–885, 2007 17293876
30 Diabetes Genetics Initiative of Broad Institute of Harvard and MIT, Lund University, and Novartis Institutes of BioMedical Research, Saxena R, Voight BF, Lyssenko V, Burtt NP, de Bakker PI, Chen H, Roix JJ, Kathiresan S, Hirschhorn JN, Daly MJ, Hughes TE, Groop L, Altshuler D, Almgren P, Florez JC, Meyer J, Ardlie K, Bengtsson Bostrom K, Isomaa B, Lettre G, Lindblad U, Lyon HN, Melander O, Newton-Cheh C, Nilsson P, Orho-Melander M, Rastam L, Speliotes EK, Taskinen MR, Tuomi T, Guiducci C, Berglund A, Carlson J, Gianniny L, Hackett R, Hall L, Holmkvist J, Laurila E, Sjogren M, Sterner M, Surti A, Svensson M, Svensson M, Tewhey R, Blumenstiel B, Parkin M, Defelice M, Barry R, Brodeur W, Camarata J, Chia N, Fava M, Gibbons J, Handsaker B, Healy C, Nguyen K, Gates C, Sougnez C, Gage D, Nizzari M, Gabriel SB, Chirn GW, Ma Q, Parikh H, Richardson D, Ricke D, Purcell S: Genome-wide association analysis identifies loci for type 2 diabetes and triglyceride levels. Science 316:1331–1336, 2007 17463246
31 Zeggini E, Weedon MN, Lindgren CM, Frayling TM, Elliott KS, Lango H, Timpson NJ, Perry JR, Rayner NW, Freathy RM, Barrett JC, Shields B, Morris AP, Ellard S, Groves CJ, Harries LW, Marchini JL, Owen KR, Knight B, Cardon LR, Walker M, Hitman GA, Morris AD, Doney AS; Wellcome Trust Case Control Consortium (WTCCC), McCarthy MI, Hattersley AT: Replication of genome-wide association signals in U.K. samples reveals risk loci for type 2 diabetes. Science 316:1336–1341, 2007 17463249
32 Scott LJ, Mohlke KL, Bonnycastle LL, Willer CJ, Li Y, Duren WL, Erdos MR, Stringham HM, Chines PS, Jackson AU, Prokunina-Olsson L, Ding CJ, Swift AJ, Narisu N, Hu T, Pruim R, Xiao R, Li XY, Conneely KN, Riebow NL, Sprau AG, Tong M, White PP, Hetrick KN, Barnhart MW, Bark CW, Goldstein JL, Watkins L, Xiang F, Saramies J, Buchanan TA, Watanabe RM, Valle TT, Kinnunen L, Abecasis GR, Pugh EW, Doheny KF, Bergman RN, Tuomilehto J, Collins FS, Boehnke M: A genome-wide association study of type 2 diabetes in Finns detects multiple susceptibility variants. Science 316:1341–1345, 2007 17463248
33 Steinthorsdottir V, Thorleifsson G, Reynisdottir I, Benediktsson R, Jonsdottir T, Walters GB, Styrkarsdottir U, Gretarsdottir S, Emilsson V, Ghosh S, Baker A, Snorradottir S, Bjarnason H, Ng MC, Hansen T, Bagger Y, Wilensky RL, Reilly MP, Adeyemo A, Chen Y, Zhou J, Gudnason V, Chen G, Huang H, Lashley K, Doumatey A, So WY, Ma RC, Andersen G, Borch-Johnsen K, Jorgensen T, van Vliet-Ostaptchouk JV, Hofker MH, Wijmenga C, Christiansen C, Rader DJ, Rotimi C, Gurney M, Chan JC, Pedersen O, Sigurdsson G, Gulcher JR, Thorsteinsdottir U, Kong A, Stefansson K: A variant in CDKAL1 influences insulin response and risk of type 2 diabetes. Nat Genet 39:770–775, 2007 17460697
34 Zeggini E, Scott LJ, Saxena R, Voight BF, Marchini JL, Hu T, de Bakker PI, Abecasis GR, Almgren P, Andersen G, Ardlie K, Bostrom KB, Bergman RN, Bonnycastle LL, Borch-Johnsen K, Burtt NP, Chen H, Chines PS, Daly MJ, Deodhar P, Ding CJ, Doney AS, Duren WL, Elliott KS, Erdos MR, Frayling TM, Freathy RM, Gianniny L, Grallert H, Grarup N, Groves CJ, Guiducci C, Hansen T, Herder C, Hitman GA, Hughes TE, Isomaa B, Jackson AU, Jorgensen T, Kong A, Kubalanza K, Kuruvilla FG, Kuusisto J, Langenberg C, Lango H, Lauritzen T, Li Y, Lindgren CM, Lyssenko V, Marvelle AF, Meisinger C, Midthjell K, Mohlke KL, Morken MA, Morris AD, Narisu N, Nilsson P, Owen KR, Palmer CN, Payne F, Perry JR, Pettersen E, Platou C, Prokopenko I, Qi L, Qin L, Rayner NW, Rees M, Roix JJ, Sandbaek A, Shields B, Sjogren M, Steinthorsdottir V, Stringham HM, Swift AJ, Thorleifsson G, Thorsteinsdottir U, Timpson NJ, Tuomi T, Tuomilehto J, Walker M, Watanabe RM, Weedon MN, Willer CJ; Wellcome Trust Case Control Consortium, Illig T, Hveem K, Hu FB, Laakso M, Stefansson K, Pedersen O, Wareham NJ, Barroso I, Hattersley AT, Collins FS, Groop L, McCarthy MI, Boehnke M, Altshuler D: Meta-analysis of genome-wide association data and large-scale replication identifies additional susceptibility loci for type 2 diabetes. Nat Genet 40:638–645, 2008 18372903
35 Voight BF, Scott LJ, Steinthorsdottir V, Morris AP, Dina C, Welch RP, Zeggini E, Huth C, Aulchenko YS, Thorleifsson G, McCulloch LJ, Ferreira T, Grallert H, Amin N, Wu G, Willer CJ, Raychaudhuri S, McCarroll SA, Langenberg C, Hofmann OM, Dupuis J, Qi L, Segre AV, van Hoek M, Navarro P, Ardlie K, Balkau B, Benediktsson R, Bennett AJ, Blagieva R, Boerwinkle E, Bonnycastle LL, Bengtsson Bostrom K, Bravenboer B, Bumpstead S, Burtt NP, Charpentier G, Chines PS, Cornelis M, Couper DJ, Crawford G, Doney AS, Elliott KS, Elliott AL, Erdos MR, Fox CS, Franklin CS, Ganser M, Gieger C, Grarup N, Green T, Griffin S, Groves CJ, Guiducci C, Hadjadj S, Hassanali N, Herder C, Isomaa B, Jackson AU, Johnson PR, Jorgensen T, Kao WH, Klopp N, Kong A, Kraft P, Kuusisto J, Lauritzen T, Li M, Lieverse A, Lindgren CM, Lyssenko V, Marre M, Meitinger T, Midthjell K, Morken MA, Narisu N, Nilsson P, Owen KR, Payne F, Perry JR, Petersen AK, Platou C, Proenca C, Prokopenko I, Rathmann W, Rayner NW, Robertson NR, Rocheleau G, Roden M, Sampson MJ, Saxena R, Shields BM, Shrader P, Sigurdsson G, Sparso T, Strassburger K, Stringham HM, Sun Q, Swift AJ, Thorand B, Tichet J, Tuomi T, van Dam RM, van Haeften TW, van Herpt T, van Vliet-Ostaptchouk JV, Walters GB, Weedon MN, Wijmenga C, Witteman J, Bergman RN, Cauchi S, Collins FS, Gloyn AL, Gyllensten U, Hansen T, Hide WA, Hitman GA, Hofman A, Hunter DJ, Hveem K, Laakso M, Mohlke KL, Morris AD, Palmer CN, Pramstaller PP, Rudan I, Sijbrands E, Stein LD, Tuomilehto J, Uitterlinden A, Walker M, Wareham NJ, Watanabe RM, Abecasis GR, Boehm BO, Campbell H, Daly MJ, Hattersley AT, Hu FB, Meigs JB, Pankow JS, Pedersen O, Wichmann HE, Barroso I, Florez JC, Frayling TM, Groop L, Sladek R, Thorsteinsdottir U, Wilson JF, Illig T, Froguel P, van Duijn CM, Stefansson K, Altshuler D, Boehnke M, McCarthy MI; MAGIC Investigators; GIANT Consortium: Twelve type 2 diabetes susceptibility loci identified through large-scale association analysis. Nat Genet 42:579–589, 2010 20581827
36 McCarthy MI: Genomics, type 2 diabetes, and obesity. N Engl J Med 363:2339–2350, 2010 21142536
37 Mohlke KL, Boehnke M: Recent advances in understanding the genetic architecture of type 2 diabetes. Human Mol Genet 24:R85–R92, 2015 26160912
38 Prokopenko I, Langenberg C, Florez JC, Saxena R, Soranzo N, Thorleifsson G, Loos RJ, Manning AK, Jackson AU, Aulchenko Y, Potter SC, Erdos MR, Sanna S, Hottenga JJ, Wheeler E, Kaakinen M, Lyssenko V, Chen WM, Ahmadi K, Beckmann JS, Bergman RN, Bochud M, Bonnycastle LL, Buchanan TA, Cao A, Cervino A, Coin L, Collins FS, Crisponi L, de Geus EJ, Dehghan A, Deloukas P, Doney AS, Elliott P, Freimer N, Gateva V, Herder C, Hofman A, Hughes TE, Hunt S, Illig T, Inouye M, Isomaa B, Johnson T, Kong A, Krestyaninova M, Kuusisto J, Laakso M, Lim N, Lindblad U, Lindgren CM, McCann OT, Mohlke KL, Morris AD, Naitza S, Orru M, Palmer CN, Pouta A, Randall J, Rathmann W, Saramies J, Scheet P, Scott LJ, Scuteri A, Sharp S, Sijbrands E, Smit JH, Song K, Steinthorsdottir V, Stringham HM, Tuomi T, Tuomilehto J, Uitterlinden AG, Voight BF, Waterworth D, Wichmann HE, Willemsen G, Witteman JC, Yuan X, Zhao JH, Zeggini E, Schlessinger D, Sandhu M, Boomsma DI, Uda M, Spector TD, Penninx BW, Altshuler D, Vollenweider P, Jarvelin MR, Lakatta E, Waeber G, Fox CS, Peltonen L, Groop LC, Mooser V, Cupples LA, Thorsteinsdottir U, Boehnke M, Barroso I, Van Duijn C, Dupuis J, Watanabe RM, Stefansson K, McCarthy MI, Wareham NJ, Meigs JB, Abecasis GR: Variants in MTNR1B influence fasting glucose levels. Nat Genet 41:77–81, 2009 19060907
39 Dupuis J, Langenberg C, Prokopenko I, Saxena R, Soranzo N, Jackson AU, Wheeler E, Glazer NL, Bouatia-Naji N, Gloyn AL, Lindgren CM, Magi R, Morris AP, Randall J, Johnson T, Elliott P, Rybin D, Thorleifsson G, Steinthorsdottir V, Henneman P, Grallert H, Dehghan A, Hottenga JJ, Franklin CS, Navarro P, Song K, Goel A, Perry JR, Egan JM, Lajunen T, Grarup N, Sparso T, Doney A, Voight BF, Stringham HM, Li M, Kanoni S, Shrader P, Cavalcanti-Proenca C, Kumari M, Qi L, Timpson NJ, Gieger C, Zabena C, Rocheleau G, Ingelsson E, An P, O’Connell J, Luan J, Elliott A, McCarroll SA, Payne F, Roccasecca RM, Pattou F, Sethupathy P, Ardlie K, Ariyurek Y, Balkau B, Barter P, Beilby JP, Ben-Shlomo Y, Benediktsson R, Bennett AJ, Bergmann S, Bochud M, Boerwinkle E, Bonnefond A, Bonnycastle LL, Borch-Johnsen K, Bottcher Y, Brunner E, Bumpstead SJ, Charpentier G, Chen YD, Chines P, Clarke R, Coin LJ, Cooper MN, Cornelis M, Crawford G, Crisponi L, Day IN, de Geus EJ, Delplanque J, Dina C, Erdos MR, Fedson AC, Fischer-Rosinsky A, Forouhi NG, Fox CS, Frants R, Franzosi MG, Galan P, Goodarzi MO, Graessler J, Groves CJ, Grundy S, Gwilliam R, Gyllensten U, Hadjadj S, Hallmans G, Hammond N, Han X, Hartikainen AL, Hassanali N, Hayward C, Heath SC, Hercberg S, Herder C, Hicks AA, Hillman DR, Hingorani AD, Hofman A, Hui J, Hung J, Isomaa B, Johnson PR, Jorgensen T, Jula A, Kaakinen M, Kaprio J, Kesaniemi YA, Kivimaki M, Knight B, Koskinen S, Kovacs P, Kyvik KO, Lathrop GM, Lawlor DA, Le Bacquer O, Lecoeur C, Li Y, Lyssenko V, Mahley R, Mangino M, Manning AK, Martinez-Larrad MT, McAteer JB, McCulloch LJ, McPherson R, Meisinger C, Melzer D, Meyre D, Mitchell BD, Morken MA, Mukherjee S, Naitza S, Narisu N, Neville MJ, Oostra BA, Orru M, Pakyz R, Palmer CN, Paolisso G, Pattaro C, Pearson D, Peden JF, Pedersen NL, Perola M, Pfeiffer AF, Pichler I, Polasek O, Posthuma D, Potter SC, Pouta A, Province MA, Psaty BM, Rathmann W, Rayner NW, Rice K, Ripatti S, Rivadeneira F, Roden M, Rolandsson O, Sandbaek A, Sandhu M, Sanna S, Sayer AA, Scheet P, Scott LJ, Seedorf U, Sharp SJ, Shields B, Sigurethsson G, Sijbrands EJ, Silveira A, Simpson L, Singleton A, Smith NL, Sovio U, Swift A, Syddall H, Syvanen AC, Tanaka T, Thorand B, Tichet J, Tonjes A, Tuomi T, Uitterlinden AG, van Dijk KW, van Hoek M, Varma D, Visvikis-Siest S, Vitart V, Vogelzangs N, Waeber G, Wagner PJ, Walley A, Walters GB, Ward KL, Watkins H, Weedon MN, Wild SH, Willemsen G, Witteman JC, Yarnell JW, Zeggini E, Zelenika D, Zethelius B, Zhai G, Zhao JH, Zillikens MC; DIAGRAM Consortium; GIANT Consortium; Global BPgen Consortium, Borecki IB, Loos RJ, Meneton P, Magnusson PK, Nathan DM, Williams GH, Hattersley AT, Silander K, Salomaa V, Smith GD, Bornstein SR, Schwarz P, Spranger J, Karpe F, Shuldiner AR, Cooper C, Dedoussis GV, Serrano-Rios M, Morris AD, Lind L, Palmer LJ, Hu FB, Franks PW, Ebrahim S, Marmot M, Kao WH, Pankow JS, Sampson MJ, Kuusisto J, Laakso M, Hansen T, Pedersen O, Pramstaller PP, Wichmann HE, Illig T, Rudan I, Wright AF, Stumvoll M, Campbell H, Wilson JF; Anders Hamsten on behalf of Procardis Consortium; MAGIC Investigators, Bergman RN, Buchanan TA, Collins FS, Mohlke KL, Tuomilehto J, Valle TT, Altshuler D, Rotter JI, Siscovick DS, Penninx BW, Boomsma DI, Deloukas P, Spector TD, Frayling TM, Ferrucci L, Kong A, Thorsteinsdottir U, Stefansson K, van Duijn CM, Aulchenko YS, Cao A, Scuteri A, Schlessinger D, Uda M, Ruokonen A, Jarvelin MR, Waterworth DM, Vollenweider P, Peltonen L, Mooser V, Abecasis GR, Wareham NJ, Sladek R, Froguel P, Watanabe RM, Meigs JB, Groop L, Boehnke M, McCarthy MI, Florez JC, Barroso I: New genetic loci implicated in fasting glucose homeostasis and their impact on type 2 diabetes risk. Nat Genet 42:105–116, 2010 20081858
40 Saxena R, Hivert MF, Langenberg C, Tanaka T, Pankow JS, Vollenweider P, Lyssenko V, Bouatia-Naji N, Dupuis J, Jackson AU, Kao WH, Li M, Glazer NL, Manning AK, Luan J, Stringham HM, Prokopenko I, Johnson T, Grarup N, Boesgaard TW, Lecoeur C, Shrader P, O’Connell J, Ingelsson E, Couper DJ, Rice K, Song K, Andreasen CH, Dina C, Kottgen A, Le Bacquer O, Pattou F, Taneera J, Steinthorsdottir V, Rybin D, Ardlie K, Sampson M, Qi L, van Hoek M, Weedon MN, Aulchenko YS, Voight BF, Grallert H, Balkau B, Bergman RN, Bielinski SJ, Bonnefond A, Bonnycastle LL, Borch-Johnsen K, Bottcher Y, Brunner E, Buchanan TA, Bumpstead SJ, Cavalcanti-Proenca C, Charpentier G, Chen YD, Chines PS, Collins FS, Cornelis M, Crawford GJ, Delplanque J, Doney A, Egan JM, Erdos MR, Firmann M, Forouhi NG, Fox CS, Goodarzi MO, Graessler J, Hingorani A, Isomaa B, Jorgensen T, Kivimaki M, Kovacs P, Krohn K, Kumari M, Lauritzen T, Levy-Marchal C, Mayor V, McAteer JB, Meyre D, Mitchell BD, Mohlke KL, Morken MA, Narisu N, Palmer CN, Pakyz R, Pascoe L, Payne F, Pearson D, Rathmann W, Sandbaek A, Sayer AA, Scott LJ, Sharp SJ, Sijbrands E, Singleton A, Siscovick DS, Smith NL, Sparso T, Swift AJ, Syddall H, Thorleifsson G, Tonjes A, Tuomi T, Tuomilehto J, Valle TT, Waeber G, Walley A, Waterworth DM, Zeggini E, Zhao JH; GIANT Consortium; MAGIC Investigators, Illig T, Wichmann HE, Wilson JF, van Duijn C, Hu FB, Morris AD, Frayling TM, Hattersley AT, Thorsteinsdottir U, Stefansson K, Nilsson P, Syvanen AC, Shuldiner AR, Walker M, Bornstein SR, Schwarz P, Williams GH, Nathan DM, Kuusisto J, Laakso M, Cooper C, Marmot M, Ferrucci L, Mooser V, Stumvoll M, Loos RJ, Altshuler D, Psaty BM, Rotter JI, Boerwinkle E, Hansen T, Pedersen O, Florez JC, McCarthy MI, Boehnke M, Barroso I, Sladek R, Froguel P, Meigs JB, Groop L, Wareham NJ, Watanabe RM: Genetic variation in GIPR influences the glucose and insulin responses to an oral glucose challenge. Nat Genet 42:142–148, 2010 20081857
41 Soranzo N, Sanna S, Wheeler E, Gieger C, Radke D, Dupuis J, Bouatia-Naji N, Langenberg C, Prokopenko I, Stolerman E, Sandhu MS, Heeney MM, Devaney JM, Reilly MP, Ricketts SL, Stewart AF, Voight BF, Willenborg C, Wright B, Altshuler D, Arking D, Balkau B, Barnes D, Boerwinkle E, Bohm B, Bonnefond A, Bonnycastle LL, Boomsma DI, Bornstein SR, Bottcher Y, Bumpstead S, Burnett-Miller MS, Campbell H, Cao A, Chambers J, Clark R, Collins FS, Coresh J, de Geus EJ, Dei M, Deloukas P, Doring A, Egan JM, Elosua R, Ferrucci L, Forouhi N, Fox CS, Franklin C, Franzosi MG, Gallina S, Goel A, Graessler J, Grallert H, Greinacher A, Hadley D, Hall A, Hamsten A, Hayward C, Heath S, Herder C, Homuth G, Hottenga JJ, Hunter-Merrill R, Illig T, Jackson AU, Jula A, Kleber M, Knouff CW, Kong A, Kooner J, Kottgen A, Kovacs P, Krohn K, Kuhnel B, Kuusisto J, Laakso M, Lathrop M, Lecoeur C, Li M, Loos RJ, Luan J, Lyssenko V, Magi R, Magnusson PK, Malarstig A, Mangino M, Martinez-Larrad MT, Marz W, McArdle WL, McPherson R, Meisinger C, Meitinger T, Melander O, Mohlke KL, Mooser VE, Morken MA, Narisu N, Nathan DM, Nauck M, O’Donnell C, Oexle K, Olla N, Pankow JS, Payne F, Peden JF, Pedersen NL, Peltonen L, Perola M, Polasek O, Porcu E, Rader DJ, Rathmann W, Ripatti S, Rocheleau G, Roden M, Rudan I, Salomaa V, Saxena R, Schlessinger D, Schunkert H, Schwarz P, Seedorf U, Selvin E, Serrano-Rios M, Shrader P, Silveira A, Siscovick D, Song K, Spector TD, Stefansson K, Steinthorsdottir V, Strachan DP, Strawbridge R, Stumvoll M, Surakka I, Swift AJ, Tanaka T, Teumer A, Thorleifsson G, Thorsteinsdottir U, Tonjes A, Usala G, Vitart V, Volzke H, Wallaschofski H, Waterworth DM, Watkins H, Wichmann HE, Wild SH, Willemsen G, Williams GH, Wilson JF, Winkelmann J, Wright AF; WTCCC, Zabena C, Zhao JH, Epstein SE, Erdmann J, Hakonarson HH, Kathiresan S, Khaw KT, Roberts R, Samani NJ, Fleming MD, Sladek R, Abecasis G, Boehnke M, Froguel P, Groop L, McCarthy MI, Kao WH, Florez JC, Uda M, Wareham NJ, Barroso I, Meigs JB: Common variants at 10 genomic loci influence hemoglobin A1(C) levels via glycemic and nonglycemic pathways. Diabetes 59:3229–3239, 2010 20858683
42 Strawbridge RJ, Dupuis J, Prokopenko I, Barker A, Ahlqvist E, Rybin D, Petrie JR, Travers ME, Bouatia-Naji N, Dimas AS, Nica A, Wheeler E, Chen H, Voight BF, Taneera J, Kanoni S, Peden JF, Turrini F, Gustafsson S, Zabena C, Almgren P, Barker DJ, Barnes D, Dennison EM, Eriksson JG, Eriksson P, Eury E, Folkersen L, Fox CS, Frayling TM, Goel A, Gu HF, Horikoshi M, Isomaa B, Jackson AU, Jameson KA, Kajantie E, Kerr-Conte J, Kuulasmaa T, Kuusisto J, Loos RJ, Luan J, Makrilakis K, Manning AK, Martinez-Larrad MT, Narisu N, Nastase Mannila M, Ohrvik J, Osmond C, Pascoe L, Payne F, Sayer AA, Sennblad B, Silveira A, Stancakova A, Stirrups K, Swift AJ, Syvanen AC, Tuomi T, van ’t Hooft FM, Walker M, Weedon MN, Xie W, Zethelius B; DIAGRAM Consortium; GIANT Consortium; MuTHER Consortium; CARDIoGRAM Consortium; C4D Consortium, Ongen H, Malarstig A, Hopewell JC, Saleheen D, Chambers J, Parish S, Danesh J, Kooner J, Ostenson CG, Lind L, Cooper CC, Serrano-Rios M, Ferrannini E, Forsen TJ, Clarke R, Franzosi MG, Seedorf U, Watkins H, Froguel P, Johnson P, Deloukas P, Collins FS, Laakso M, Dermitzakis ET, Boehnke M, McCarthy MI, Wareham NJ, Groop L, Pattou F, Gloyn AL, Dedoussis GV, Lyssenko V, Meigs JB, Barroso I, Watanabe RM, Ingelsson E, Langenberg C, Hamsten A, Florez JC: Genome-wide association identifies nine common variants associated with fasting proinsulin levels and provides new insights into the pathophysiology of type 2 diabetes. Diabetes 60:2624–2634, 2011 21873549
43 Manning AK, Hivert MF, Scott RA, Grimsby JL, Bouatia-Naji N, Chen H, Rybin D, Liu CT, Bielak LF, Prokopenko I, Amin N, Barnes D, Cadby G, Hottenga JJ, Ingelsson E, Jackson AU, Johnson T, Kanoni S, Ladenvall C, Lagou V, Lahti J, Lecoeur C, Liu Y, Martinez-Larrad MT, Montasser ME, Navarro P, Perry JR, Rasmussen-Torvik LJ, Salo P, Sattar N, Shungin D, Strawbridge RJ, Tanaka T, van Duijn CM, An P, de Andrade M, Andrews JS, Aspelund T, Atalay M, Aulchenko Y, Balkau B, Bandinelli S, Beckmann JS, Beilby JP, Bellis C, Bergman RN, Blangero J, Boban M, Boehnke M, Boerwinkle E, Bonnycastle LL, Boomsma DI, Borecki IB, Bottcher Y, Bouchard C, Brunner E, Budimir D, Campbell H, Carlson O, Chines PS, Clarke R, Collins FS, Corbaton-Anchuelo A, Couper D, de Faire U, Dedoussis GV, Deloukas P, Dimitriou M, Egan JM, Eiriksdottir G, Erdos MR, Eriksson JG, Eury E, Ferrucci L, Ford I, Forouhi NG, Fox CS, Franzosi MG, Franks PW, Frayling TM, Froguel P, Galan P, de Geus E, Gigante B, Glazer NL, Goel A, Groop L, Gudnason V, Hallmans G, Hamsten A, Hansson O, Harris TB, Hayward C, Heath S, Hercberg S, Hicks AA, Hingorani A, Hofman A, Hui J, Hung J, Jarvelin MR, Jhun MA, Johnson PC, Jukema JW, Jula A, Kao WH, Kaprio J, Kardia SL, Keinanen-Kiukaanniemi S, Kivimaki M, Kolcic I, Kovacs P, Kumari M, Kuusisto J, Kyvik KO, Laakso M, Lakka T, Lannfelt L, Lathrop GM, Launer LJ, Leander K, Li G, Lind L, Lindstrom J, Lobbens S, Loos RJ, Luan J, Lyssenko V, Magi R, Magnusson PK, Marmot M, Meneton P, Mohlke KL, Mooser V, Morken MA, Miljkovic I, Narisu N, O’Connell J, Ong KK, Oostra BA, Palmer LJ, Palotie A, Pankow JS, Peden JF, Pedersen NL, Pehlic M, Peltonen L, Penninx B, Pericic M, Perola M, Perusse L, Peyser PA, Polasek O, Pramstaller PP, Province MA, Raikkonen K, Rauramaa R, Rehnberg E, Rice K, Rotter JI, Rudan I, Ruokonen A, Saaristo T, Sabater-Lleal M, Salomaa V, Savage DB, Saxena R, Schwarz P, Seedorf U, Sennblad B, Serrano-Rios M, Shuldiner AR, Sijbrands EJ, Siscovick DS, Smit JH, Small KS, Smith NL, Smith AV, Stancakova A, Stirrups K, Stumvoll M, Sun YV, Swift AJ, Tonjes A, Tuomilehto J, Trompet S, Uitterlinden AG, Uusitupa M, Vikstrom M, Vitart V, Vohl MC, Voight BF, Vollenweider P, Waeber G, Waterworth DM, Watkins H, Wheeler E, Widen E, Wild SH, Willems SM, Willemsen G, Wilson JF, Witteman JC, Wright AF, Yaghootkar H, Zelenika D, Zemunik T, Zgaga L; DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium; Multiple Tissue Human Expression Resource (MuTHER) Consortium, Wareham NJ, McCarthy MI, Barroso I, Watanabe RM, Florez JC, Dupuis J, Meigs JB, Langenberg C: A genome-wide approach accounting for body mass index identifies genetic variants influencing fasting glycemic traits and insulin resistance. Nat Genet 44:659–669, 2012 22581228
44 Prokopenko I, Poon W, Magi R, Prasad BR, Salehi SA, Almgren P, Osmark P, Bouatia-Naji N, Wierup N, Fall T, Stancakova A, Barker A, Lagou V, Osmond C, Xie W, Lahti J, Jackson AU, Cheng YC, Liu J, O’Connell JR, Blomstedt PA, Fadista J, Alkayyali S, Dayeh T, Ahlqvist E, Taneera J, Lecoeur C, Kumar A, Hansson O, Hansson K, Voight BF, Kang HM, Levy-Marchal C, Vatin V, Palotie A, Syvanen AC, Mari A, Weedon MN, Loos RJ, Ong KK, Nilsson P, Isomaa B, Tuomi T, Wareham NJ, Stumvoll M, Widen E, Lakka TA, Langenberg C, Tonjes A, Rauramaa R, Kuusisto J, Frayling TM, Froguel P, Walker M, Eriksson JG, Ling C, Kovacs P, Ingelsson E, McCarthy MI, Shuldiner AR, Silver KD, Laakso M, Groop L, Lyssenko V: A central role for GRB10 in regulation of islet function in man. PLoS Genet 10:e1004235, 2014 24699409
45 Knowles JW, Xie W, Zhang Z, Chennamsetty I, Assimes TL, Paananen J, Hansson O, Pankow J, Goodarzi MO, Carcamo-Orive I, Morris AP, Chen YD, Makinen VP, Ganna A, Mahajan A, Guo X, Abbasi F, Greenawalt DM, Lum P, Molony C, Lind L, Lindgren C, Raffel LJ, Tsao PS; RISC (Relationship between Insulin Sensitivity and Cardiovascular Disease) Consortium; EUGENE (European Network on Functional Genomics of Type Diabetes) Study; GUARDIAN (Genetics UndeRlying DIAbetes in HispaNics) Consortium; SAPPHIRe (Stanford Asian and Pacific Program for Hypertension and Insulin Resistance) Study, Schadt EE, Rotter JI, Sinaiko A, Reaven G, Yang X, Hsiung CA, Groop L, Cordell HJ, Laakso M, Hao K, Ingelsson E, Frayling TM, Weedon MN, Walker M, Quertermous T: Identification and validation of N-acetyltransferase 2 as an insulin sensitivity gene. J Clin Invest 126:403, 2016 26727231
46 Unoki H, Takahashi A, Kawaguchi T, Hara K, Horikoshi M, Andersen G, Ng DP, Holmkvist J, Borch-Johnsen K, Jorgensen T, Sandbaek A, Lauritzen T, Hansen T, Nurbaya S, Tsunoda T, Kubo M, Babazono T, Hirose H, Hayashi M, Iwamoto Y, Kashiwagi A, Kaku K, Kawamori R, Tai ES, Pedersen O, Kamatani N, Kadowaki T, Kikkawa R, Nakamura Y, Maeda S: SNPs in KCNQ1 are associated with susceptibility to type 2 diabetes in East Asian and European populations. Nat Genet 40:1098–1102, 2008 18711366
47 Yasuda K, Miyake K, Horikawa Y, Hara K, Osawa H, Furuta H, Hirota Y, Mori H, Jonsson A, Sato Y, Yamagata K, Hinokio Y, Wang HY, Tanahashi T, Nakamura N, Oka Y, Iwasaki N, Iwamoto Y, Yamada Y, Seino Y, Maegawa H, Kashiwagi A, Takeda J, Maeda E, Shin HD, Cho YM, Park KS, Lee HK, Ng MC, Ma RC, So WY, Chan JC, Lyssenko V, Tuomi T, Nilsson P, Groop L, Kamatani N, Sekine A, Nakamura Y, Yamamoto K, Yoshida T, Tokunaga K, Itakura M, Makino H, Nanjo K, Kadowaki T, Kasuga M: Variants in KCNQ1 are associated with susceptibility to type 2 diabetes mellitus. Nat Genet 40:1092–1097, 2008 18711367
48 Tsai FJ, Yang CF, Chen CC, Chuang LM, Lu CH, Chang CT, Wang TY, Chen RH, Shiu CF, Liu YM, Chang CC, Chen P, Chen CH, Fann CS, Chen YT, Wu JY: A genome-wide association study identifies susceptibility variants for type 2 diabetes in Han Chinese. PLoS Genet 6:e1000847, 2010 20174558
49 Shu XO, Long J, Cai Q, Qi L, Xiang YB, Cho YS, Tai ES, Li X, Lin X, Chow WH, Go MJ, Seielstad M, Bao W, Li H, Cornelis MC, Yu K, Wen W, Shi J, Han BG, Sim XL, Liu L, Qi Q, Kim HL, Ng DP, Lee JY, Kim YJ, Li C, Gao YT, Zheng W, Hu FB: Identification of new genetic risk variants for type 2 diabetes. PLoS Genet 6:e1001127, 2010 20862305
50 Yamauchi T, Hara K, Maeda S, Yasuda K, Takahashi A, Horikoshi M, Nakamura M, Fujita H, Grarup N, Cauchi S, Ng DP, Ma RC, Tsunoda T, Kubo M, Watada H, Maegawa H, Okada-Iwabu M, Iwabu M, Shojima N, Shin HD, Andersen G, Witte DR, Jorgensen T, Lauritzen T, Sandbaek A, Hansen T, Ohshige T, Omori S, Saito I, Kaku K, Hirose H, So WY, Beury D, Chan JC, Park KS, Tai ES, Ito C, Tanaka Y, Kashiwagi A, Kawamori R, Kasuga M, Froguel P, Pedersen O, Kamatani N, Nakamura Y, Kadowaki T: A genome-wide association study in the Japanese population identifies susceptibility loci for type 2 diabetes at UBE2E2 and C2CD4A-C2CD4B. Nat Genet 42:864–868, 2010 20818381
51 Kooner JS, Saleheen D, Sim X, Sehmi J, Zhang W, Frossard P, Been LF, Chia KS, Dimas AS, Hassanali N, Jafar T, Jowett JBM, Li X, Radha V, Rees SD, Takeuchi F, Young R, Aung T, Basit A, Chidambaram M, Das D, Grundberg E, Hedman AK, Hydrie ZI, Islam M, Khor CC, Kowlessur S, Kristensen MM, Liju S, Lim WY, Matthews DR, Liu J, Morris AP, Nica AC, Pinidiyapathirage JM, Prokopenko I, Rasheed A, Samuel M, Shah N, Shera AS, Small KS, Suo C, Wickremasinghe AR, Wong TY, Yang M, Zhang F; DIAGRAM; MuTHER, Abecasis GR, Barnett AH, Caulfield M, Deloukas P, Frayling TM, Froguel P, Kato N, Katulanda P, Kelly MA, Liang J, Mohan V, Sanghera DK, Scott J, Seielstad M, Zimmet PZ, Elliott P, Teo YY, McCarthy MI, Danesh J, Tai ES, Chambers JC: Genome-wide association study in individuals of South Asian ancestry identifies six new type 2 diabetes susceptibility loci. Nat Genet 43:984–989, 2011 21874001
52 Parra EJ, Below JE, Krithika S, Valladares A, Barta JL, Cox NJ, Hanis CL, Wacher N, Garcia-Mena J, Hu P, Shriver MD; DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium, Kumate J, McKeigue PM, Escobedo J, Cruz M: Genome-wide association study of type 2 diabetes in a sample from Mexico City and a meta-analysis of a Mexican-American sample from Starr County, Texas. Diabetologia 54:2038–2046, 2011 21573907
53 Below JE, Gamazon ER, Morrison JV, Konkashbaev A, Pluzhnikov A, McKeigue PM, Parra EJ, Elbein SC, Hallman DM, Nicolae DL, Bell GI, Cruz M, Cox NJ, Hanis CL: Genome-wide association and meta-analysis in populations from Starr County, Texas, and Mexico City identify type 2 diabetes susceptibility loci and enrichment for expression quantitative trait loci in top signals. Diabetologia 54:2047–2055, 2011 21647700
54 Palmer ND, McDonough CW, Hicks PJ, Roh BH, Wing MR, An SS, Hester JM, Cooke JN, Bostrom MA, Rudock ME, Talbert ME, Lewis JP; DIAGRAM Consortium; MAGIC Investigators, Ferrara A, Lu L, Ziegler JT, Sale MM, Divers J, Shriner D, Adeyemo A, Rotimi CN, Ng MC, Langefeld CD, Freedman BI, Bowden DW, Voight BF, Scott LJ, Steinthorsdottir V, Morris AP, Dina C, Welch RP, Zeggini E, Huth C, Aulchenko YS, Thorleifsson G, McCulloch LJ, Ferreira T, Grallert H, Amin N, Wu G, Willer CJ, Raychaudhuri S, McCarroll SA, Langenberg C, Hofmann OM, Dupuis J, Qi L, Segre AV, van Hoek M, Navarro P, Ardlie K, Balkau B, Benediktsson R, Bennett AJ, Blagieva R, Boerwinkle E, Bonnycastle LL, Bostrom KB, Bravenboer B, Bumpstead S, Burtt NP, Charpentier G, Chines PS, Cornelis M, Couper DJ, Crawford G, Doney AS, Elliott KS, Elliott AL, Erdos MR, Fox CS, Franklin CS, Ganser M, Gieger C, Grarup N, Green T, Griffin S, Groves CJ, Guiducci C, Hadjadj S, Hassanali N, Herder C, Isomaa B, Jackson AU, Johnson PR, Jorgensen T, Kao WH, Klopp N, Kong A, Kraft P, Kuusisto J, Lauritzen T, Li M, Lieverse A, Lindgren CM, Lyssenko V, Marre M, Meitinger T, Midthjell K, Morken MA, Narisu N, Nilsson P, Owen KR, Payne F, Perry JR, Petersen AK, Platou C, Proenca C, Prokopenko I, Rathmann W, Rayner NW, Robertson NR, Rocheleau G, Roden M, Sampson MJ, Saxena R, Shields BM, Shrader P, Sigurdsson G, Sparso T, Strassburger K, Stringham HM, Sun Q, Swift AJ, Thorand B, Tichet J, Tuomi T, van Dam RM, van Haeften TW, van Herpt T, van Vliet-Ostaptchouk JV, Walters GB, Weedon MN, Wijmenga C, Witteman J, Bergman RN, Cauchi S, Collins FS, Gloyn AL, Gyllensten U, Hansen T, Hide WA, Hitman GA, Hofman A, Hunter DJ, Hveem K, Laakso M, Mohlke KL, Morris AD, Palmer CN, Pramstaller PP, Rudan I, Sijbrands E, Stein LD, Tuomilehto J, Uitterlinden A, Walker M, Wareham NJ, Watanabe RM, Abecasis GR, Boehm BO, Campbell H, Daly MJ, Hattersley AT, Hu FB, Meigs JB, Pankow JS, Pedersen O, Wichmann HE, Barroso I, Florez JC, Frayling TM, Groop L, Sladek R, Thorsteinsdottir U, Wilson JF, Illig T, Froguel P, van Duijn CM, Stefansson K, Altshuler D, Boehnke M, McCarthy MI, Soranzo N, Wheeler E, Glazer NL, Bouatia-Naji N, Magi R, Randall J, Johnson T, Elliott P, Rybin D, Henneman P, Dehghan A, Hottenga JJ, Song K, Goel A, Egan JM, Lajunen T, Doney A, Kanoni S, Cavalcanti-Proenca C, Kumari M, Timpson NJ, Zabena C, Ingelsson E, An P, O’Connell J, Luan J, Elliott A, McCarroll SA, Roccasecca RM, Pattou F, Sethupathy P, Ariyurek Y, Barter P, Beilby JP, Ben-Shlomo Y, Bergmann S, Bochud M, Bonnefond A, Borch-Johnsen K, Bottcher Y, Brunner E, Bumpstead SJ, Chen YD, Chines P, Clarke R, Coin LJ, Cooper MN, Crisponi L, Day IN, de Geus EJ, Delplanque J, Fedson AC, Fischer-Rosinsky A, Forouhi NG, Frants R, Franzosi MG, Galan P, Goodarzi MO, Graessler J, Grundy S, Gwilliam R, Hallmans G, Hammond N, Han X, Hartikainen AL, Hayward C, Heath SC, Hercberg S, Hicks AA, Hillman DR, Hingorani AD, Hui J, Hung J, Jula A, Kaakinen M, Kaprio J, Kesaniemi YA, Kivimaki M, Knight B, Koskinen S, Kovacs P, Kyvik KO, Lathrop GM, Lawlor DA, Le Bacquer O, Lecoeur C, Li Y, Mahley R, Mangino M, Manning AK, Martinez-Larrad MT, McAteer JB, McPherson R, Meisinger C, Melzer D, Meyre D, Mitchell BD, Mukherjee S, Naitza S, Neville MJ, Oostra BA, Orru M, Pakyz R, Paolisso G, Pattaro C, Pearson D, Peden JF, Pedersen NL, Perola M, Pfeiffer AF, Pichler I, Polasek O, Posthuma D, Potter SC, Pouta A, Province MA, Psaty BM, Rayner NW, Rice K, Ripatti S, Rivadeneira F, Rolandsson O, Sandbaek A, Sandhu M, Sanna S, Sayer AA, Scheet P, Seedorf U, Sharp SJ, Shields B, Sijbrands EJ, Silveira A, Simpson L, Singleton A, Smith NL, Sovio U, Swift A, Syddall H, Syvanen AC, Tanaka T, Tonjes A, Uitterlinden AG, van Dijk KW, Varma D, Visvikis-Siest S, Vitart V, Vogelzangs N, Waeber G, Wagner PJ, Walley A, Ward KL, Watkins H, Wild SH, Willemsen G, Witteman JC, Yarnell JW, Zelenika D, Zethelius B, Zhai G, Zhao JH, Zillikens MC, Borecki IB, Loos RJ, Meneton P, Magnusson PK, Nathan DM, Williams GH, Silander K, Salomaa V, Smith GD, Bornstein SR, Schwarz P, Spranger J, Karpe F, Shuldiner AR, Cooper C, Dedoussis GV, Serrano-Rios M, Lind L, Palmer LJ, Franks PW, Ebrahim S, Marmot M, Kao WH, Pramstaller PP, Wright AF, Stumvoll M, Hamsten A, Buchanan TA, Valle TT, Rotter JI, Siscovick DS, Penninx BW, Boomsma DI, Deloukas P, Spector TD, Ferrucci L, Cao A, Scuteri A, Schlessinger D, Uda M, Ruokonen A, Jarvelin MR, Waterworth DM, Vollenweider P, Peltonen L, Mooser V, Sladek R: A genome-wide association search for type 2 diabetes genes in African Americans. PLoS One 7:e29202, 2012 22238593
55 Cho YS, Chen CH, Hu C, Long J, Ong RT, Sim X, Takeuchi F, Wu Y, Go MJ, Yamauchi T, Chang YC, Kwak SH, Ma RC, Yamamoto K, Adair LS, Aung T, Cai Q, Chang LC, Chen YT, Gao Y, Hu FB, Kim HL, Kim S, Kim YJ, Lee JJ, Lee NR, Li Y, Liu JJ, Lu W, Nakamura J, Nakashima E, Ng DP, Tay WT, Tsai FJ, Wong TY, Yokota M, Zheng W, Zhang R, Wang C, So WY, Ohnaka K, Ikegami H, Hara K, Cho YM, Cho NH, Chang TJ, Bao Y, Hedman AK, Morris AP, McCarthy MI; DIAGRAM Consortium; MuTHER Consortium, Takayanagi R, Park KS, Jia W, Chuang LM, Chan JC, Maeda S, Kadowaki T, Lee JY, Wu JY, Teo YY, Tai ES, Shu XO, Mohlke KL, Kato N, Han BG, Seielstad M: Meta-analysis of genome-wide association studies identifies eight new loci for type 2 diabetes in East Asians. Nat Genet 44:67–72, 2011 22158537
56 Saxena R, Elbers CC, Guo Y, Peter I, Gaunt TR, Mega JL, Lanktree MB, Tare A, Castillo BA, Li YR, Johnson T, Bruinenberg M, Gilbert-Diamond D, Rajagopalan R, Voight BF, Balasubramanyam A, Barnard J, Bauer F, Baumert J, Bhangale T, Bohm BO, Braund PS, Burton PR, Chandrupatla HR, Clarke R, Cooper-DeHoff RM, Crook ED, Davey-Smith G, Day IN, de Boer A, de Groot MC, Drenos F, Ferguson J, Fox CS, Furlong CE, Gibson Q, Gieger C, Gilhuijs-Pederson LA, Glessner JT, Goel A, Gong Y, Grant SF, Grobbee DE, Hastie C, Humphries SE, Kim CE, Kivimaki M, Kleber M, Meisinger C, Kumari M, Langaee TY, Lawlor DA, Li M, Lobmeyer MT, Maitland-van der Zee AH, Meijs MF, Molony CM, Morrow DA, Murugesan G, Musani SK, Nelson CP, Newhouse SJ, O’Connell JR, Padmanabhan S, Palmen J, Patel SR, Pepine CJ, Pettinger M, Price TS, Rafelt S, Ranchalis J, Rasheed A, Rosenthal E, Ruczinski I, Shah S, Shen H, Silbernagel G, Smith EN, Spijkerman AW, Stanton A, Steffes MW, Thorand B, Trip M, van der Harst P, van der A DL, van Iperen EP, van Setten J, van Vliet-Ostaptchouk JV, Verweij N, Wolffenbuttel BH, Young T, Zafarmand MH, Zmuda JM; Look AHEAD Research Group; DIAGRAM Consortium, Boehnke M, Altshuler D, McCarthy M, Kao WH, Pankow JS, Cappola TP, Sever P, Poulter N, Caulfield M, Dominiczak A, Shields DC, Bhatt DL, Zhang L, Curtis SP, Danesh J, Casas JP, van der Schouw YT, Onland-Moret NC, Doevendans PA, Dorn GW, Jr., Farrall M, FitzGerald GA, Hamsten A, Hegele R, Hingorani AD, Hofker MH, Huggins GS, Illig T, Jarvik GP, Johnson JA, Klungel OH, Knowler WC, Koenig W, Marz W, Meigs JB, Melander O, Munroe PB, Mitchell BD, Bielinski SJ, Rader DJ, Reilly MP, Rich SS, Rotter JI, Saleheen D, Samani NJ, Schadt EE, Shuldiner AR, Silverstein R, Kottke-Marchant K, Talmud PJ, Watkins H, Asselbergs FW, de Bakker PI, McCaffery J, Wijmenga C, Sabatine MS, Wilson JG, Reiner A, Bowden DW, Hakonarson H, Siscovick DS, Keating BJ: Large-scale gene-centric meta-analysis across 39 studies identifies type 2 diabetes loci. Am J Hum Genet 90:410–425, 2012 22325160
57 Li H, Gan W, Lu L, Dong X, Han X, Hu C, Yang Z, Sun L, Bao W, Li P, He M, Sun L, Wang Y, Zhu J, Ning Q, Tang Y, Zhang R, Wen J, Wang D, Zhu X, Guo K, Zuo X, Guo X, Yang H, Zhou X; DIAGRAM Consortium; AGEN-T2D Consortium, Zhang X, Qi L, Loos RJ, Hu FB, Wu T, Liu Y, Liu L, Yang Z, Hu R, Jia W, Ji L, Li Y, Lin X: A genome-wide association study identifies GRK5 and RASGRP1 as type 2 diabetes loci in Chinese Hans. Diabetes 62:291–298, 2013 22961080
58 Tabassum R, Chauhan G, Dwivedi OP, Mahajan A, Jaiswal A, Kaur I, Bandesh K, Singh T, Mathai BJ, Pandey Y, Chidambaram M, Sharma A, Chavali S, Sengupta S, Ramakrishnan L, Venkatesh P, Aggarwal SK, Ghosh S, Prabhakaran D, Srinath RK, Saxena M, Banerjee M, Mathur S, Bhansali A, Shah VN, Madhu SV, Marwaha RK, Basu A, Scaria V, McCarthy MI; DIAGRAM; INDICO, Venkatesan R, Mohan V, Tandon N, Bharadwaj D: Genome-wide association study for type 2 diabetes in Indians identifies a new susceptibility locus at 2q21. Diabetes 62:977–986, 2013 23209189
59 Saxena R, Saleheen D, Been LF, Garavito ML, Braun T, Bjonnes A, Young R, Ho WK, Rasheed A, Frossard P, Sim X, Hassanali N, Radha V, Chidambaram M, Liju S, Rees SD, Ng DP, Wong TY, Yamauchi T, Hara K, Tanaka Y, Hirose H, McCarthy MI, Morris AP; DIAGRAM; MuTHER; AGEN, Basit A, Barnett AH, Katulanda P, Matthews D, Mohan V, Wander GS, Singh JR, Mehra NK, Ralhan S, Kamboh MI, Mulvihill JJ, Maegawa H, Tobe K, Maeda S, Cho YS, Tai ES, Kelly MA, Chambers JC, Kooner JS, Kadowaki T, Deloukas P, Rader DJ, Danesh J, Sanghera DK: Genome-wide association study identifies a novel locus contributing to type 2 diabetes susceptibility in Sikhs of Punjabi origin from India. Diabetes 62:1746–1755, 2013 23300278
60 Go MJ, Hwang JY, Park TJ, Kim YJ, Oh JH, Kim YJ, Han BG, Kim BJ: Genome-wide association study identifies two novel loci with sex-specific effects for type 2 diabetes mellitus and glycemic traits in a Korean population. Diabetes Metab J 38:375–387, 2014 25349825
61 SIGMA Type 2 Diabetes Consortium; Williams AL, Jacobs SB, Moreno-Macias H, Huerta-Chagoya A, Churchhouse C, Marquez-Luna C, Garcia-Ortiz H, Gomez-Vazquez MJ, Burtt NP, Aguilar-Salinas CA, Gonzalez-Villalpando C, Florez JC, Orozco L, Haiman CA, Tusie-Luna T, Altshuler D: Sequence variants in SLC16A11 are a common risk factor for type 2 diabetes in Mexico. Nature 506:97–101, 2014 24390345
62 Hara K, Fujita H, Johnson TA, Yamauchi T, Yasuda K, Horikoshi M, Peng C, Hu C, Ma RC, Imamura M, Iwata M, Tsunoda T, Morizono T, Shojima N, So WY, Leung TF, Kwan P, Zhang R, Wang J, Yu W, Maegawa H, Hirose H; DIAGRAM Consortium, Kaku K, Ito C, Watada H, Tanaka Y, Tobe K, Kashiwagi A, Kawamori R, Jia W, Chan JC, Teo YY, Shyong TE, Kamatani N, Kubo M, Maeda S, Kadowaki T: Genome-wide association study identifies three novel loci for type 2 diabetes. Hum Mol Genet 23:239–246, 2014 23945395
63 Ng MC, Shriner D, Chen BH, Li J, Chen WM, Guo X, Liu J, Bielinski SJ, Yanek LR, Nalls MA, Comeau ME, Rasmussen-Torvik LJ, Jensen RA, Evans DS, Sun YV, An P, Patel SR, Lu Y, Long J, Armstrong LL, Wagenknecht L, Yang L, Snively BM, Palmer ND, Mudgal P, Langefeld CD, Keene KL, Freedman BI, Mychaleckyj JC, Nayak U, Raffel LJ, Goodarzi MO, Chen YD, Taylor HA, Jr., Correa A, Sims M, Couper D, Pankow JS, Boerwinkle E, Adeyemo A, Doumatey A, Chen G, Mathias RA, Vaidya D, Singleton AB, Zonderman AB, Igo RP, Jr., Sedor JR; FIND Consortium, Kabagambe EK, Siscovick DS, McKnight B, Rice K, Liu Y, Hsueh WC, Zhao W, Bielak LF, Kraja A, Province MA, Bottinger EP, Gottesman O, Cai Q, Zheng W, Blot WJ, Lowe WL, Pacheco JA, Crawford DC; eMERGE Consortium; DIAGRAM Consortium, Grundberg E; MuTHER Consortium, Rich SS, Hayes MG, Shu XO, Loos RJ, Borecki IB, Peyser PA, Cummings SR, Psaty BM, Fornage M, Iyengar SK, Evans MK, Becker DM, Kao WH, Wilson JG, Rotter JI, Sale MM, Liu S, Rotimi CN, Bowden DW; MEta-analysis of type 2 DIabetes in African Americans (MEDIA) Consortium: Meta-analysis of genome-wide association studies in African Americans provides insights into the genetic architecture of type 2 diabetes. PLoS Genet 10:e1004517, 2014 25102180
64 Hanson RL, Muller YL, Kobes S, Guo T, Bian L, Ossowski V, Wiedrich K, Sutherland J, Wiedrich C, Mahkee D, Huang K, Abdussamad M, Traurig M, Weil EJ, Nelson RG, Bennett PH, Knowler WC, Bogardus C, Baier LJ: A genome-wide association study in American Indians implicates DNER as a susceptibility locus for type 2 diabetes. Diabetes 63:369–376, 2014 24101674
65 DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium; Asian Genetic Epidemiology Network Type 2 Diabetes (AGEN-T2D) Consortium; South Asian Type 2 Diabetes (SAT2D) Consortium; Mexican American Type 2 Diabetes (MAT2D) Consortium; Type 2 Diabetes Genetic Exploration by Nex-generation sequencing in muylti-Ethnic Samples (T2D-GENES) Consortium, Mahajan A, Go MJ, Zhang W, Below JE, Gaulton KJ, Ferreira T, Horikoshi M, Johnson AD, Ng MC, Prokopenko I, Saleheen D, Wang X, Zeggini E, Abecasis GR, Adair LS, Almgren P, Atalay M, Aung T, Baldassarre D, Balkau B, Bao Y, Barnett AH, Barroso I, Basit A, Been LF, Beilby J, Bell GI, Benediktsson R, Bergman RN, Boehm BO, Boerwinkle E, Bonnycastle LL, Burtt N, Cai Q, Campbell H, Carey J, Cauchi S, Caulfield M, Chan JC, Chang LC, Chang TJ, Chang YC, Charpentier G, Chen CH, Chen H, Chen YT, Chia KS, Chidambaram M, Chines PS, Cho NH, Cho YM, Chuang LM, Collins FS, Cornelis MC, Couper DJ, Crenshaw AT, van Dam RM, Danesh J, Das D, de Faire U, Dedoussis G, Deloukas P, Dimas AS, Dina C, Doney AS, Donnelly PJ, Dorkhan M, van Duijn C, Dupuis J, Edkins S, Elliott P, Emilsson V, Erbel R, Eriksson JG, Escobedo J, Esko T, Eury E, Florez JC, Fontanillas P, Forouhi NG, Forsen T, Fox C, Fraser RM, Frayling TM, Froguel P, Frossard P, Gao Y, Gertow K, Gieger C, Gigante B, Grallert H, Grant GB, Groop LC, Groves CJ, Grundberg E, Guiducci C, Hamsten A, Han BG, Hara K, Hassanali N, Hattersley AT, Hayward C, Hedman AK, Herder C, Hofman A, Holmen OL, Hovingh K, Hreidarsson AB, Hu C, Hu FB, Hui J, Humphries SE, Hunt SE, Hunter DJ, Hveem K, Hydrie ZI, Ikegami H, Illig T, Ingelsson E, Islam M, Isomaa B, Jackson AU, Jafar T, James A, Jia W, Jockel KH, Jonsson A, Jowett JB, Kadowaki T, Kang HM, Kanoni S, Kao WH, Kathiresan S, Kato N, Katulanda P, Keinanen-Kiukaanniemi KM, Kelly AM, Khan H, Khaw KT, Khor CC, Kim HL, Kim S, Kim YJ, Kinnunen L, Klopp N, Kong A, Korpi-Hyovalti E, Kowlessur S, Kraft P, Kravic J, Kristensen MM, Krithika S, Kumar A, Kumate J, Kuusisto J, Kwak SH, Laakso M, Lagou V, Lakka TA, Langenberg C, Langford C, Lawrence R, Leander K, Lee JM, Lee NR, Li M, Li X, Li Y, Liang J, Liju S, Lim WY, Lind L, Lindgren CM, Lindholm E, Liu CT, Liu JJ, Lobbens S, Long J, Loos RJ, Lu W, Luan J, Lyssenko V, Ma RC, Maeda S, Magi R, Mannisto S, Matthews DR, Meigs JB, Melander O, Metspalu A, Meyer J, Mirza G, Mihailov E, Moebus S, Mohan V, Mohlke KL, Morris AD, Muhleisen TW, Muller-Nurasyid M, Musk B, Nakamura J, Nakashima E, Navarro P, Ng PK, Nica AC, Nilsson PM, Njolstad I, Nothen MM, Ohnaka K, Ong TH, Owen KR, Palmer CN, Pankow JS, Park KS, Parkin M, Pechlivanis S, Pedersen NL, Peltonen L, Perry JR, Peters A, Pinidiyapathirage JM, Platou CG, Potter S, Price JF, Qi L, Radha V, Rallidis L, Rasheed A, Rathman W, Rauramaa R, Raychaudhuri S, Rayner NW, Rees SD, Rehnberg E, Ripatti S, Robertson N, Roden M, Rossin EJ, Rudan I, Rybin D, Saaristo TE, Salomaa V, Saltevo J, Samuel M, Sanghera DK, Saramies J, Scott J, Scott LJ, Scott RA, Segre AV, Sehmi J, Sennblad B, Shah N, Shah S, Shera AS, Shu XO, Shuldiner AR, Sigurdsson G, Sijbrands E, Silveira A, Sim X, Sivapalaratnam S, Small KS, So WY, Stancakova A, Stefansson K, Steinbach G, Steinthorsdottir V, Stirrups K, Strawbridge RJ, Stringham HM, Sun Q, Suo C, Syvanen AC, Takayanagi R, Takeuchi F, Tay WT, Teslovich TM, Thorand B, Thorleifsson G, Thorsteinsdottir U, Tikkanen E, Trakalo J, Tremoli E, Trip MD, Tsai FJ, Tuomi T, Tuomilehto J, Uitterlinden AG, Valladares-Salgado A, Vedantam S, Veglia F, Voight BF, Wang C, Wareham NJ, Wennauer R, Wickremasinghe AR, Wilsgaard T, Wilson JF, Wiltshire S, Winckler W, Wong TY, Wood AR, Wu JY, Wu Y, Yamamoto K, Yamauchi T, Yang M, Yengo L, Yokota M, Young R, Zabaneh D, Zhang F, Zhang R, Zheng W, Zimmet PZ, Altshuler D, Bowden DW, Cho YS, Cox NJ, Cruz M, Hanis CL, Kooner J, Lee JY, Seielstad M, Teo YY, Boehnke M, Parra EJ, Chambers JC, Tai ES, McCarthy MI, Morris AP: Genome-wide trans-ancestry meta-analysis provides insight into the genetic architecture of type 2 diabetes susceptibility. Nat Genet 46:234–244, 2014 24509480
66 Morris AP, Voight BF, Teslovich TM, Ferreira T, Segre AV, Steinthorsdottir V, Strawbridge RJ, Khan H, Grallert H, Mahajan A, Prokopenko I, Kang HM, Dina C, Esko T, Fraser RM, Kanoni S, Kumar A, Lagou V, Langenberg C, Luan J, Lindgren CM, Muller-Nurasyid M, Pechlivanis S, Rayner NW, Scott LJ, Wiltshire S, Yengo L, Kinnunen L, Rossin EJ, Raychaudhuri S, Johnson AD, Dimas AS, Loos RJ, Vedantam S, Chen H, Florez JC, Fox C, Liu CT, Rybin D, Couper DJ, Kao WH, Li M, Cornelis MC, Kraft P, Sun Q, van Dam RM, Stringham HM, Chines PS, Fischer K, Fontanillas P, Holmen OL, Hunt SE, Jackson AU, Kong A, Lawrence R, Meyer J, Perry JR, Platou CG, Potter S, Rehnberg E, Robertson N, Sivapalaratnam S, Stancakova A, Stirrups K, Thorleifsson G, Tikkanen E, Wood AR, Almgren P, Atalay M, Benediktsson R, Bonnycastle LL, Burtt N, Carey J, Charpentier G, Crenshaw AT, Doney AS, Dorkhan M, Edkins S, Emilsson V, Eury E, Forsen T, Gertow K, Gigante B, Grant GB, Groves CJ, Guiducci C, Herder C, Hreidarsson AB, Hui J, James A, Jonsson A, Rathmann W, Klopp N, Kravic J, Krjutskov K, Langford C, Leander K, Lindholm E, Lobbens S, Mannisto S, Mirza G, Muhleisen TW, Musk B, Parkin M, Rallidis L, Saramies J, Sennblad B, Shah S, Sigurdsson G, Silveira A, Steinbach G, Thorand B, Trakalo J, Veglia F, Wennauer R, Winckler W, Zabaneh D, Campbell H, van Duijn C, Uitterlinden AG, Hofman A, Sijbrands E, Abecasis GR, Owen KR, Zeggini E, Trip MD, Forouhi NG, Syvanen AC, Eriksson JG, Peltonen L, Nothen MM, Balkau B, Palmer CN, Lyssenko V, Tuomi T, Isomaa B, Hunter DJ, Qi L; Wellcome Trust Case Control Consortium; Meta-Analyses of Glucose and Insulin-related traits Consortium (MAGIC) Investigators; Genetic Investigation of ANthropometric Traits (GIANT) Consortium; Asian Genetic Epidemiology Network–Type 2 Diabetes (AGEN-T2D) Consortium; South Asian Type 2 Diabetes (SAT2D) Consortium, Shuldiner AR, Roden M, Barroso I, Wilsgaard T, Beilby J, Hovingh K, Price JF, Wilson JF, Rauramaa R, Lakka TA, Lind L, Dedoussis G, Njolstad I, Pedersen NL, Khaw KT, Wareham NJ, Keinanen-Kiukaanniemi SM, Saaristo TE, Korpi-Hyovalti E, Saltevo J, Laakso M, Kuusisto J, Metspalu A, Collins FS, Mohlke KL, Bergman RN, Tuomilehto J, Boehm BO, Gieger C, Hveem K, Cauchi S, Froguel P, Baldassarre D, Tremoli E, Humphries SE, Saleheen D, Danesh J, Ingelsson E, Ripatti S, Salomaa V, Erbel R, Jockel KH, Moebus S, Peters A, Illig T, de Faire U, Hamsten A, Morris AD, Donnelly PJ, Frayling TM, Hattersley AT, Boerwinkle E, Melander O, Kathiresan S, Nilsson PM, Deloukas P, Thorsteinsdottir U, Groop LC, Stefansson K, Hu F, Pankow JS, Dupuis J, Meigs JB, Altshuler D, Boehnke M, McCarthy MI; DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium: Large-scale association analysis provides insights into the genetic architecture and pathophysiology of type 2 diabetes. Nat Genet 44:981–990, 2012 22885922
67 Scott RA, Lagou V, Welch RP, Wheeler E, Montasser ME, Luan J, Magi R, Strawbridge RJ, Rehnberg E, Gustafsson S, Kanoni S, Rasmussen-Torvik LJ, Yengo L, Lecoeur C, Shungin D, Sanna S, Sidore C, Johnson PC, Jukema JW, Johnson T, Mahajan A, Verweij N, Thorleifsson G, Hottenga JJ, Shah S, Smith AV, Sennblad B, Gieger C, Salo P, Perola M, Timpson NJ, Evans DM, Pourcain BS, Wu Y, Andrews JS, Hui J, Bielak LF, Zhao W, Horikoshi M, Navarro P, Isaacs A, O’Connell JR, Stirrups K, Vitart V, Hayward C, Esko T, Mihailov E, Fraser RM, Fall T, Voight BF, Raychaudhuri S, Chen H, Lindgren CM, Morris AP, Rayner NW, Robertson N, Rybin D, Liu CT, Beckmann JS, Willems SM, Chines PS, Jackson AU, Kang HM, Stringham HM, Song K, Tanaka T, Peden JF, Goel A, Hicks AA, An P, Muller-Nurasyid M, Franco-Cereceda A, Folkersen L, Marullo L, Jansen H, Oldehinkel AJ, Bruinenberg M, Pankow JS, North KE, Forouhi NG, Loos RJ, Edkins S, Varga TV, Hallmans G, Oksa H, Antonella M, Nagaraja R, Trompet S, Ford I, Bakker SJ, Kong A, Kumari M, Gigante B, Herder C, Munroe PB, Caulfield M, Antti J, Mangino M, Small K, Miljkovic I, Liu Y, Atalay M, Kiess W, James AL, Rivadeneira F, Uitterlinden AG, Palmer CN, Doney AS, Willemsen G, Smit JH, Campbell S, Polasek O, Bonnycastle LL, Hercberg S, Dimitriou M, Bolton JL, Fowkes GR, Kovacs P, Lindstrom J, Zemunik T, Bandinelli S, Wild SH, Basart HV, Rathmann W, Grallert H; DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium, Maerz W, Kleber ME, Boehm BO, Peters A, Pramstaller PP, Province MA, Borecki IB, Hastie ND, Rudan I, Campbell H, Watkins H, Farrall M, Stumvoll M, Ferrucci L, Waterworth DM, Bergman RN, Collins FS, Tuomilehto J, Watanabe RM, de Geus EJ, Penninx BW, Hofman A, Oostra BA, Psaty BM, Vollenweider P, Wilson JF, Wright AF, Hovingh GK, Metspalu A, Uusitupa M, Magnusson PK, Kyvik KO, Kaprio J, Price JF, Dedoussis GV, Deloukas P, Meneton P, Lind L, Boehnke M, Shuldiner AR, van Duijn CM, Morris AD, Toenjes A, Peyser PA, Beilby JP, Korner A, Kuusisto J, Laakso M, Bornstein SR, Schwarz PE, Lakka TA, Rauramaa R, Adair LS, Smith GD, Spector TD, Illig T, de Faire U, Hamsten A, Gudnason V, Kivimaki M, Hingorani A, Keinanen-Kiukaanniemi SM, Saaristo TE, Boomsma DI, Boomsma DI, Stefansson K, van der Harst P, Dupuis J, Pedersen NL, Sattar N, Harris TB, Cucca F, Ripatti S, Salomaa V, Mohlke KL, Balkau B, Froguel P, Pouta A, Jarvelin MR, Wareham NJ, Bouatia-Naji N, McCarthy MI, Franks PW, Meigs JB, Teslovich TM, Florez JC, Langenberg C, Ingelsson E, Prokopenko I, Barroso I: Large-scale association analyses identify new loci influencing glycemic traits and provide insight into the underlying biological pathways. Nat Genet 44:991–1005, 2012 22885924
68 Moltke I, Grarup N, Jorgensen ME, Bjerregaard P, Treebak JT, Fumagalli M, Korneliussen TS, Andersen MA, Nielsen TS, Krarup NT, Gjesing AP, Zierath JR, Linneberg A, Wu X, Sun G, Jin X, Al-Aama J, Wang J, Borch-Johnsen K, Pedersen O, Nielsen R, Albrechtsen A, Hansen T: A common Greenlandic TBC1D4 variant confers muscle insulin resistance and type 2 diabetes. Nature 512:190–193, 2014 25043022
69 Voight BF, Kang HM, Ding J, Palmer CD, Sidore C, Chines PS, Burtt NP, Fuchsberger C, Li Y, Erdmann J, Frayling TM, Heid IM, Jackson AU, Johnson T, Kilpelainen TO, Lindgren CM, Morris AP, Prokopenko I, Randall JC, Saxena R, Soranzo N, Speliotes EK, Teslovich TM, Wheeler E, Maguire J, Parkin M, Potter S, Rayner NW, Robertson N, Stirrups K, Winckler W, Sanna S, Mulas A, Nagaraja R, Cucca F, Barroso I, Deloukas P, Loos RJ, Kathiresan S, Munroe PB, Newton-Cheh C, Pfeufer A, Samani NJ, Schunkert H, Hirschhorn JN, Altshuler D, McCarthy MI, Abecasis GR, Boehnke M: The metabochip, a custom genotyping array for genetic studies of metabolic, cardiovascular, and anthropometric traits. PLoS Genet 8:e1002793, 2012 22876189
70 International HapMap Consortium; Frazer KA, Ballinger DG, Cox DR, Hinds DA, Stuve LL, Gibbs RA, Belmont JW, Boudreau A, Hardenbol P, Leal SM, Pasternak S, Wheeler DA, Willis TD, Yu F, Yang H, Zeng C, Gao Y, Hu H, Hu W, Li C, Lin W, Liu S, Pan H, Tang X, Wang J, Wang W, Yu J, Zhang B, Zhang Q, Zhao H, Zhao H, Zhou J, Gabriel SB, Barry R, Blumenstiel B, Camargo A, Defelice M, Faggart M, Goyette M, Gupta S, Moore J, Nguyen H, Onofrio RC, Parkin M, Roy J, Stahl E, Winchester E, Ziaugra L, Altshuler D, Shen Y, Yao Z, Huang W, Chu X, He Y, Jin L, Liu Y, Shen Y, Sun W, Wang H, Wang Y, Wang Y, Xiong X, Xu L, Waye MM, Tsui SK, Xue H, Wong JT, Galver LM, Fan JB, Gunderson K, Murray SS, Oliphant AR, Chee MS, Montpetit A, Chagnon F, Ferretti V, Leboeuf M, Olivier JF, Phillips MS, Roumy S, Sallee C, Verner A, Hudson TJ, Kwok PY, Cai D, Koboldt DC, Miller RD, Pawlikowska L, Taillon-Miller P, Xiao M, Tsui LC, Mak W, Song YQ, Tam PK, Nakamura Y, Kawaguchi T, Kitamoto T, Morizono T, Nagashima A, Ohnishi Y, Sekine A, Tanaka T, Tsunoda T, Deloukas P, Bird CP, Delgado M, Dermitzakis ET, Gwilliam R, Hunt S, Morrison J, Powell D, Stranger BE, Whittaker P, Bentley DR, Daly MJ, de Bakker PI, Barrett J, Chretien YR, Maller J, McCarroll S, Patterson N, Pe’er I, Price A, Purcell S, Richter DJ, Sabeti P, Saxena R, Schaffner SF, Sham PC, Varilly P, Altshuler D, Stein LD, Krishnan L, Smith AV, Tello-Ruiz MK, Thorisson GA, Chakravarti A, Chen PE, Cutler DJ, Kashuk CS, Lin S, Abecasis GR, Guan W, Li Y, Munro HM, Qin ZS, Thomas DJ, McVean G, Auton A, Bottolo L, Cardin N, Eyheramendy S, Freeman C, Marchini J, Myers S, Spencer C, Stephens M, Donnelly P, Cardon LR, Clarke G, Evans DM, Morris AP, Weir BS, Tsunoda T, Mullikin JC, Sherry ST, Feolo M, Skol A, Zhang H, Zeng C, Zhao H, Matsuda I, Fukushima Y, Macer DR, Suda E, Rotimi CN, Adebamowo CA, Ajayi I, Aniagwu T, Marshall PA, Nkwodimmah C, Royal CD, Leppert MF, Dixon M, Peiffer A, Qiu R, Kent A, Kato K, Niikawa N, Adewole IF, Knoppers BM, Foster MW, Clayton EW, Watkin J, Gibbs RA, Belmont JW, Muzny D, Nazareth L, Sodergren E, Weinstock GM, Wheeler DA, Yakub I, Gabriel SB, Onofrio RC, Richter DJ, Ziaugra L, Birren BW, Daly MJ, Altshuler D, Wilson RK, Fulton LL, Rogers J, Burton J, Carter NP, Clee CM, Griffiths M, Jones MC, McLay K, Plumb RW, Ross MT, Sims SK, Willey DL, Chen Z, Han H, Kang L, Godbout M, Wallenburg JC, L’Archeveque P, Bellemare G, Saeki K, Wang H, An D, Fu H, Li Q, Wang Z, Wang R, Holden AL, Brooks LD, McEwen JE, Guyer MS, Wang VO, Peterson JL, Shi M, Spiegel J, Sung LM, Zacharia LF, Collins FS, Kennedy K, Jamieson R, Stewart J: A second generation human haplotype map of over 3.1 million SNPs. Nature 449:851–861, 2007 17943122
71 1000 Genomes Project Consortium; Abecasis GR, Auton A, Brooks LD, DePristo MA, Durbin RM, Handsaker RE, Kang HM, Marth GT, McVean GA: An integrated map of genetic variation from 1,092 human genomes. Nature 491:56–65, 2012 23128226
72 Huyghe JR, Jackson AU, Fogarty MP, Buchkovich ML, Stancakova A, Stringham HM, Sim X, Yang L, Fuchsberger C, Cederberg H, Chines PS, Teslovich TM, Romm JM, Ling H, McMullen I, Ingersoll R, Pugh EW, Doheny KF, Neale BM, Daly MJ, Kuusisto J, Scott LJ, Kang HM, Collins FS, Abecasis GR, Watanabe RM, Boehnke M, Laakso M, Mohlke KL: Exome array analysis identifies new loci and low-frequency variants influencing insulin processing and secretion. Nat Genet 45:197–201, 2013 23263489
73 Wessel J, Chu AY, Willems SM, Wang S, Yaghootkar H, Brody JA, Dauriz M, Hivert MF, Raghavan S, Lipovich L, Hidalgo B, Fox K, Huffman JE, An P, Lu Y, Rasmussen-Torvik LJ, Grarup N, Ehm MG, Li L, Baldridge AS, Stancakova A, Abrol R, Besse C, Boland A, Bork-Jensen J, Fornage M, Freitag DF, Garcia ME, Guo X, Hara K, Isaacs A, Jakobsdottir J, Lange LA, Layton JC, Li M, Hua Zhao J, Meidtner K, Morrison AC, Nalls MA, Peters MJ, Sabater-Lleal M, Schurmann C, Silveira A, Smith AV, Southam L, Stoiber MH, Strawbridge RJ, Taylor KD, Varga TV, Allin KH, Amin N, Aponte JL, Aung T, Barbieri C, Bihlmeyer NA, Boehnke M, Bombieri C, Bowden DW, Burns SM, Chen Y, Chen YD, Cheng CY, Correa A, Czajkowski J, Dehghan A, Ehret GB, Eiriksdottir G, Escher SA, Farmaki AE, Franberg M, Gambaro G, Giulianini F, Goddard WA 3rd, Goel A, Gottesman O, Grove ML, Gustafsson S, Hai Y, Hallmans G, Heo J, Hoffmann P, Ikram MK, Jensen RA, Jorgensen ME, Jorgensen T, Karaleftheri M, Khor CC, Kirkpatrick A, Kraja AT, Kuusisto J, Lange EM, Lee IT, Lee WJ, Leong A, Liao J, Liu C, Liu Y, Lindgren CM, Linneberg A, Malerba G, Mamakou V, Marouli E, Maruthur NM, Matchan A, McKean-Cowdin R, McLeod O, Metcalf GA, Mohlke KL, Muzny DM, Ntalla I, Palmer ND, Pasko D, Peter A, Rayner NW, Renstrom F, Rice K, Sala CF, Sennblad B, Serafetinidis I, Smith JA, Soranzo N, Speliotes EK, Stahl EA, Stirrups K, Tentolouris N, Thanopoulou A, Torres M, Traglia M, Tsafantakis E, Javad S, Yanek LR, Zengini E, Becker DM, Bis JC, Brown JB, Cupples LA, Hansen T, Ingelsson E, Karter AJ, Lorenzo C, Mathias RA, Norris JM, Peloso GM, Sheu WH, Toniolo D, Vaidya D, Varma R, Wagenknecht LE, Boeing H, Bottinger EP, Dedoussis G, Deloukas P, Ferrannini E, Franco OH, Franks PW, Gibbs RA, Gudnason V, Hamsten A, Harris TB, Hattersley AT, Hayward C, Hofman A, Jansson JH, Langenberg C, Launer LJ, Levy D, Oostra BA, O’Donnell CJ, O’Rahilly S, Padmanabhan S, Pankow JS, Polasek O, Province MA, Rich SS, Ridker PM, Rudan I, Schulze MB, Smith BH, Uitterlinden AG, Walker M, Watkins H, Wong TY, Zeggini E; EPIC-InterAct Consortium, Laakso M, Borecki IB, Chasman DI, Pedersen O, Psaty BM, Shyong Tai E, van Duijn CM, Wareham NJ, Waterworth DM, Boerwinkle E, Linda Kao WH, Florez JC, Loos RJ, Wilson JG, Frayling TM, Siscovick DS, Dupuis J, Rotter JI, Meigs JB, Scott RA, Goodarzi MO: Low-frequency and rare exome chip variants associate with fasting glucose and type 2 diabetes susceptibility. Nat Commun 6:5897, 2015 25631608
74 Mahajan A, Sim X, Ng HJ, Manning A, Rivas MA, Highland HM, Locke AE, Grarup N, Im HK, Cingolani P, Flannick J, Fontanillas P, Fuchsberger C, Gaulton KJ, Teslovich TM, Rayner NW, Robertson NR, Beer NL, Rundle JK, Bork-Jensen J, Ladenvall C, Blancher C, Buck D, Buck G, Burtt NP, Gabriel S, Gjesing AP, Groves CJ, Hollensted M, Huyghe JR, Jackson AU, Jun G, Justesen JM, Mangino M, Murphy J, Neville M, Onofrio R, Small KS, Stringham HM, Syvanen AC, Trakalo J, Abecasis G, Bell GI, Blangero J, Cox NJ, Duggirala R, Hanis CL, Seielstad M, Wilson JG, Christensen C, Brandslund I, Rauramaa R, Surdulescu GL, Doney AS, Lannfelt L, Linneberg A, Isomaa B, Tuomi T, Jorgensen ME, Jorgensen T, Kuusisto J, Uusitupa M, Salomaa V, Spector TD, Morris AD, Palmer CN, Collins FS, Mohlke KL, Bergman RN, Ingelsson E, Lind L, Tuomilehto J, Hansen T, Watanabe RM, Prokopenko I, Dupuis J, Karpe F, Groop L, Laakso M, Pedersen O, Florez JC, Morris AP, Altshuler D, Meigs JB, Boehnke M, McCarthy MI, Lindgren CM, Gloyn AL; T2D-GENES Consortium; GoT2D Consortium: Identification and functional characterization of G6PC2 coding variants influencing glycemic traits define an effector transcript at the G6PC2-ABCB11 locus. PLoS Genet 11:e1004876, 2015 25625282
75 Albrechtsen A, Grarup N, Li Y, Sparso T, Tian G, Cao H, Jiang T, Kim SY, Korneliussen T, Li Q, Nie C, Wu R, Skotte L, Morris AP, Ladenvall C, Cauchi S, Stancakova A, Andersen G, Astrup A, Banasik K, Bennett AJ, Bolund L, Charpentier G, Chen Y, Dekker JM, Doney AS, Dorkhan M, Forsen T, Frayling TM, Groves CJ, Gui Y, Hallmans G, Hattersley AT, He K, Hitman GA, Holmkvist J, Huang S, Jiang H, Jin X, Justesen JM, Kristiansen K, Kuusisto J, Lajer M, Lantieri O, Li W, Liang H, Liao Q, Liu X, Ma T, Ma X, Manijak MP, Marre M, Mokrosinski J, Morris AD, Mu B, Nielsen AA, Nijpels G, Nilsson P, Palmer CN, Rayner NW, Renstrom F, Ribel-Madsen R, Robertson N, Rolandsson O, Rossing P, Schwartz TW; D.E.S.I.R. Study Group, Slagboom PE, Sterner M; DIAGRAM Consortium, Tang M, Tarnow L, Tuomi T, van ’t Riet E, van Leeuwen N, Varga TV, Vestmar MA, Walker M, Wang B, Wang Y, Wu H, Xi F, Yengo L, Yu C, Zhang X, Zhang J, Zhang Q, Zhang W, Zheng H, Zhou Y, Altshuler D, ’t Hart LM, Franks PW, Balkau B, Froguel P, McCarthy MI, Laakso M, Groop L, Christensen C, Brandslund I, Lauritzen T, Witte DR, Linneberg A, Jorgensen T, Hansen T, Wang J, Nielsen R, Pedersen O: Exome sequencing-driven discovery of coding polymorphisms associated with common metabolic phenotypes. Diabetologia 56:298–310, 2013 23160641
76 SIGMA Type 2 Diabetes Consortium, Estrada K, Aukrust I, Bjorkhaug L, Burtt NP, Mercader JM, Garcia-Ortiz H, Huerta-Chagoya A, Moreno-Macias H, Walford G, Flannick J, Williams AL, Gomez-Vazquez MJ, Fernandez-Lopez JC, Martinez-Hernandez A, Jimenez-Morales S, Centeno-Cruz F, Mendoza-Caamal E, Revilla-Monsalve C, Islas-Andrade S, Cordova EJ, Soberon X, Gonzalez-Villalpando ME, Henderson E, Wilkens LR, Le Marchand L, Arellano-Campos O, Ordonez-Sanchez ML, Rodriguez-Torres M, Rodriguez-Guillen R, Riba L, Najmi LA, Jacobs SB, Fennell T, Gabriel S, Fontanillas P, Hanis CL, Lehman DM, Jenkinson CP, Abboud HE, Bell GI, Cortes ML, Boehnke M, Gonzalez-Villalpando C, Orozco L, Haiman CA, Tusie-Luna T, Aguilar-Salinas CA, Altshuler D, Njolstad PR, Florez JC, MacArthur DG: Association of a low-frequency variant in HNF1A with type 2 diabetes in a Latino population. JAMA 311:2305–2314, 2014 24915262
77 Steinthorsdottir V, Thorleifsson G, Sulem P, Helgason H, Grarup N, Sigurdsson A, Helgadottir HT, Johannsdottir H, Magnusson OT, Gudjonsson SA, Justesen JM, Harder MN, Jorgensen ME, Christensen C, Brandslund I, Sandbaek A, Lauritzen T, Vestergaard H, Linneberg A, Jorgensen T, Hansen T, Daneshpour MS, Fallah MS, Hreidarsson AB, Sigurdsson G, Azizi F, Benediktsson R, Masson G, Helgason A, Kong A, Gudbjartsson DF, Pedersen O, Thorsteinsdottir U, Stefansson K: Identification of low-frequency and rare sequence variants associated with elevated or reduced risk of type 2 diabetes. Nat Genet 46:294–298, 2014 24464100
78 Fuchsberger C, Flannick J, Teslovich TM, Mahajan A, Agarwala V, Gaulton KJ, Ma C, Fontanillas P, Moutsianas L, McCarthy DJ, Rivas MA, Perry JR, Sim X, Blackwell TW, Robertson NR, Rayner NW, Cingolani P, Locke AE, Fernandez-Tajes J, Highland HM, Dupuis J, Chines PS, Lindgren CM, Hartl C, Jackson AU, Chen H, Huyghe JR, van de Bunt M, Pearson RD, Kumar A, Muller-Nurasyid M, Grarup N, Stringham HM, Gamazon ER, Lee J, Chen Y, Scott RA, Below JE, Chen P, Huang J, Go MJ, Stitzel ML, Pasko D, Parker SC, Varga TV, Green T, Beer NL, Day-Williams AG, Ferreira T, Fingerlin T, Horikoshi M, Hu C, Huh I, Ikram MK, Kim BJ, Kim Y, Kim YJ, Kwon MS, Lee J, Lee S, Lin KH, Maxwell TJ, Nagai Y, Wang X, Welch RP, Yoon J, Zhang W, Barzilai N, Voight BF, Han BG, Jenkinson CP, Kuulasmaa T, Kuusisto J, Manning A, Ng MC, Palmer ND, Balkau B, Stancakova A, Abboud HE, Boeing H, Giedraitis V, Prabhakaran D, Gottesman O, Scott J, Carey J, Kwan P, Grant G, Smith JD, Neale BM, Purcell S, Butterworth AS, Howson JM, Lee HM, Lu Y, Kwak SH, Zhao W, Danesh J, Lam VK, Park KS, Saleheen D, So WY, Tam CH, Afzal U, Aguilar D, Arya R, Aung T, Chan E, Navarro C, Cheng CY, Palli D, Correa A, Curran JE, Rybin D, Farook VS, Fowler SP, Freedman BI, Griswold M, Hale DE, Hicks PJ, Khor CC, Kumar S, Lehne B, Thuillier D, Lim WY, Liu J, van der Schouw YT, Loh M, Musani SK, Puppala S, Scott WR, Yengo L, Tan ST, Taylor HA, Jr., Thameem F, Wilson G, Sr., Wong TY, Njolstad PR, Levy JC, Mangino M, Bonnycastle LL, Schwarzmayr T, Fadista J, Surdulescu GL, Herder C, Groves CJ, Wieland T, Bork-Jensen J, Brandslund I, Christensen C, Koistinen HA, Doney AS, Kinnunen L, Esko T, Farmer AJ, Hakaste L, Hodgkiss D, Kravic J, Lyssenko V, Hollensted M, Jorgensen ME, Jorgensen T, Ladenvall C, Justesen JM, Karajamaki A, Kriebel J, Rathmann W, Lannfelt L, Lauritzen T, Narisu N, Linneberg A, Melander O, Milani L, Neville M, Orho-Melander M, Qi L, Qi Q, Roden M, Rolandsson O, Swift A, Rosengren AH, Stirrups K, Wood AR, Mihailov E, Blancher C, Carneiro MO, Maguire J, Poplin R, Shakir K, Fennell T, DePristo M, Hrabe de Angelis M, Deloukas P, Gjesing AP, Jun G, Nilsson P, Murphy J, Onofrio R, Thorand B, Hansen T, Meisinger C, Hu FB, Isomaa B, Karpe F, Liang L, Peters A, Huth C, O’Rahilly SP, Palmer CNA, Pedersen O, Rauramaa R, Tuomilehto J, Salomaa V, Watanabe RM, Syvanen AC, Bergman RN, Bharadwaj D, Bottinger EP, Cho YS, Chandak GR, Chan JC, Chia KS, Daly MJ, Ebrahim SB, Langenberg C, Elliott P, Jablonski KA, Lehman DM, Jia W, Ma RC, Pollin TI, Sandhu M, Tandon N, Froguel P, Barroso I, Teo YY, Zeggini E, Loos RJ, Small KS, Ried JS, DeFronzo RA, Grallert H, Glaser B, Metspalu A, Wareham NJ, Walker M, Banks E, Gieger C, Ingelsson E, Im HK, Illig T, Franks PW, Buck G, Trakalo J, Buck D, Prokopenko I, Magi R, Lind L, Farjoun Y, Owen KR, Gloyn AL, Strauch K, Tuomi T, Kooner JS, Lee JY, Park T, Donnelly P, Morris AD, Hattersley AT, Bowden DW, Collins FS, Atzmon G, Chambers JC, Spector TD, Laakso M, Strom TM, Bell GI, Blangero J, Duggirala R, Tai ES, McVean G, Hanis CL, Wilson JG, Seielstad M, Frayling TM, Meigs JB, Cox NJ, Sladek R, Lander ES, Gabriel S, Burtt NP, Mohlke KL, Meitinger T, Groop L, Abecasis G, Florez JC, Scott LJ, Morris AP, Kang HM, Boehnke M, Altshuler D, McCarthy MI: The genetic architecture of type 2 diabetes. Nature 536:41–47, 2016 27398621
79 ENCODE Project Consortium: An integrated encyclopedia of DNA elements in the human genome. Nature 489:57–74, 2012 22955616
80 Dickson SP, Wang K, Krantz I, Hakonarson H, Goldstein DB: Rare variants create synthetic genome-wide associations. PLoS Biol 8:e1000294, 2010 20126254
81 Stahl EA, Wegmann D, Trynka G, Gutierrez-Achury J, Do R, Voight BF, Kraft P, Chen R, Kallberg HJ, Kurreeman FA; Diabetes Genetics Replication and Meta-analysis Consortium; Myocardial Infarction Genetics Consortium, Kathiresan S, Wijmenga C, Gregersen PK, Alfredsson L, Siminovitch KA, Worthington J, de Bakker PI, Raychaudhuri S, Plenge RM: Bayesian inference analyses of the polygenic architecture of rheumatoid arthritis. Nat Genet 44:483–489, 2012 22446960
82 Florez JC: Newly identified loci highlight beta cell dysfunction as a key cause of type 2 diabetes: where are the insulin resistance genes? Diabetologia 51:1100–1110, 2008 18504548
83 Dimas AS, Lagou V, Barker A, Knowles JW, Magi R, Hivert MF, Benazzo A, Rybin D, Jackson AU, Stringham HM, Song C, Fischer-Rosinsky A, Boesgaard TW, Grarup N, Abbasi FA, Assimes TL, Hao K, Yang X, Lecoeur C, Barroso I, Bonnycastle LL, Bottcher Y, Bumpstead S, Chines PS, Erdos MR, Graessler J, Kovacs P, Morken MA, Narisu N, Payne F, Stancakova A, Swift AJ, Tonjes A, Bornstein SR, Cauchi S, Froguel P, Meyre D, Schwarz PE, Haring HU, Smith U, Boehnke M, Bergman RN, Collins FS, Mohlke KL, Tuomilehto J, Quertemous T, Lind L, Hansen T, Pedersen O, Walker M, Pfeiffer AF, Spranger J, Stumvoll M, Meigs JB, Wareham NJ, Kuusisto J, Laakso M, Langenberg C, Dupuis J, Watanabe RM, Florez JC, Ingelsson E, McCarthy MI, Prokopenko I: Impact of type 2 diabetes susceptibility variants on quantitative glycemic traits reveals mechanistic heterogeneity. Diabetes 63:2158–2171, 2014 24296717
84 Bergman RN, Zaccaro DJ, Watanabe RM, Haffner SM, Saad MF, Norris JM, Wagenknecht LE, Hokanson JE, Rotter JI, Rich SS: Minimal model-based insulin sensitivity has greater heritability and a different genetic basis than homeostasis model assessment or fasting insulin. Diabetes 52:2168–2174, 2003 12882937
85 Pan A, Schernhammer ES, Sun Q, Hu FB: Rotating night shift work and risk of type 2 diabetes: two prospective cohort studies in women. PLoS Med 8:e1001141, 2011 22162955
86 Turek FW, Joshu C, Kohsaka A, Lin E, Ivanova G, McDearmon E, Laposky A, Losee-Olson S, Easton A, Jensen DR, Eckel RH, Takahashi JS, Bass J: Obesity and metabolic syndrome in circadian Clock mutant mice. Science 308:1043–1045, 2005 15845877
87 Marcheva B, Ramsey KM, Buhr ED, Kobayashi Y, Su H, Ko CH, Ivanova G, Omura C, Mo S, Vitaterna MH, Lopez JP, Philipson LH, Bradfield CA, Crosby SD, JeBailey L, Wang X, Takahashi JS, Bass J: Disruption of the clock components CLOCK and BMAL1 leads to hypoinsulinaemia and diabetes. Nature 466:627–631, 2010 20562852
88 Buxton OM, Cain SW, O’Connor SP, Porter JH, Duffy JF, Wang W, Czeisler CA, Shea SA: Adverse metabolic consequences in humans of prolonged sleep restriction combined with circadian disruption. Sci Transl Med 4:129ra43, 2012
89 Freathy RM, Mook-Kanamori DO, Sovio U, Prokopenko I, Timpson NJ, Berry DJ, Warrington NM, Widen E, Hottenga JJ, Kaakinen M, Lange LA, Bradfield JP, Kerkhof M, Marsh JA, Magi R, Chen CM, Lyon HN, Kirin M, Adair LS, Aulchenko YS, Bennett AJ, Borja JB, Bouatia-Naji N, Charoen P, Coin LJ, Cousminer DL, de Geus EJ, Deloukas P, Elliott P, Evans DM, Froguel P; Genetic Investigation of ANthropometric Traits (GIANT) Consortium, Glaser B, Groves CJ, Hartikainen AL, Hassanali N, Hirschhorn JN, Hofman A, Holly JM, Hypponen E, Kanoni S, Knight BA, Laitinen J, Lindgren CM; Meta-Analyses of Glucose and Insulin-related Traits Consortium, McArdle WL, O’Reilly PF, Pennell CE, Postma DS, Pouta A, Ramasamy A, Rayner NW, Ring SM, Rivadeneira F, Shields BM, Strachan DP, Surakka I, Taanila A, Tiesler C, Uitterlinden AG, van Duijn CM; Wellcome Trust Case Control Consortium, Wijga AH, Willemsen G, Zhang H, Zhao J, Wilson JF, Steegers EA, Hattersley AT, Eriksson JG, Peltonen L, Mohlke KL, Grant SF, Hakonarson H, Koppelman GH, Dedoussis GV, Heinrich J, Gillman MW, Palmer LJ, Frayling TM, Boomsma DI, Davey Smith G, Power C, Jaddoe VW, Jarvelin MR; Early Growth Genetics (EGG) Consortium, McCarthy MI: Variants in ADCY5 and near CCNL1 are associated with fetal growth and birth weight. Nat Genet 42:430–435, 2010 20372150
90 Chambers JC, Elliott P, Zabaneh D, Zhang W, Li Y, Froguel P, Balding D, Scott J, Kooner JS: Common genetic variation near MC4R is associated with waist circumference and insulin resistance. Nat Genet 40:716–718, 2008 18454146
91 Waters KM, Stram DO, Hassanein MT, Le Marchand L, Wilkens LR, Maskarinec G, Monroe KR, Kolonel LN, Altshuler D, Henderson BE, Haiman CA: Consistent association of type 2 diabetes risk variants found in Europeans in diverse racial and ethnic groups. PLoS Genet 6:e1001078, 2010 20865176
92 Yang Q, Liu T, Shrader P, Yesupriya A, Chang MH, Dowling NF, Ned RM, Dupuis J, Florez JC, Khoury MJ, Meigs JB; MAGIC Investigators: Racial/ethnic differences in association of fasting glucose-associated genomic loci with fasting glucose, HOMA-B, and impaired fasting glucose in the U.S. adult population. Diabetes Care 33:2370–2377, 2010 20805255
93 Haiman CA, Fesinmeyer MD, Spencer KL, Buzkova P, Voruganti VS, Wan P, Haessler J, Franceschini N, Monroe KR, Howard BV, Jackson RD, Florez JC, Kolonel LN, Buyske S, Goodloe RJ, Liu S, Manson JE, Meigs JB, Waters K, Mukamal KJ, Pendergrass SA, Shrader P, Wilkens LR, Hindorff LA, Ambite JL, North KE, Peters U, Crawford DC, Le Marchand L, Pankow JS: Consistent directions of effect for established type 2 diabetes risk variants across populations: the Population Architecture using Genomics and Epidemiology (PAGE) Consortium. Diabetes 61:1642–1647, 2012 22474029
94 Meigs JB, Shrader P, Sullivan LM, McAteer JB, Fox CS, Dupuis J, Manning AK, Florez JC, Wilson PW, D’Agostino RB, Sr., Cupples LA: Genotype score in addition to common risk factors for prediction of type 2 diabetes. N Engl J Med 359:2208–2219, 2008 19020323
95 Lyssenko V, Jonsson A, Almgren P, Pulizzi N, Isomaa B, Tuomi T, Berglund G, Altshuler D, Nilsson P, Groop L: Clinical risk factors, DNA variants, and the development of type 2 diabetes. N Engl J Med 359:2220–2232, 2008 19020324
96 de Miguel-Yanes JM, Shrader P, Pencina MJ, Fox CS, Manning AK, Grant RW, Dupuis J, Florez JC, D’Agostino RB, Sr., Cupples LA, Meigs JB; MAGIC Investigators; DIAGRAM+ Investigators: Genetic risk reclassification for type 2 diabetes by age below or above 50 years using 40 type 2 diabetes risk single nucleotide polymorphisms. Diabetes Care 34:121–125, 2011 20889853
97 Hivert MF, Jablonski KA, Perreault L, Saxena R, McAteer JB, Franks PW, Hamman RF, Kahn SE, Haffner S; DIAGRAM Consortium, Meigs JB, Altshuler D, Knowler WC, Florez JC; Diabetes Prevention Program Research Group: Updated genetic score based on 34 confirmed type 2 diabetes loci is associated with diabetes incidence and regression to normoglycemia in the Diabetes Prevention Program. Diabetes 60:1340–1348, 2011 21378175
98 Vaxillaire M, Froguel P: Monogenic diabetes in the young, pharmacogenetics and relevance to multifactorial forms of type 2 diabetes. Endocr Rev 29:254–264, 2008 18436708
99 Greeley SA, Naylor RN, Philipson LH, Bell GI: Neonatal diabetes: an expanding list of genes allows for improved diagnosis and treatment. Curr Diab Rep 11:519–532, 2011 21993633
100 Becker ML, Visser LE, van Schaik RHN, Hofman A, Uitterlinden AG, Stricker BHC: Genetic variation in the multidrug and toxin extrusion 1 transporter protein influences the glucose-lowering effect of metformin in patients with diabetes: a preliminary study. Diabetes 58:745–749, 2009 19228809
101 Jablonski KA, McAteer JB, de Bakker PI, Franks PW, Pollin TI, Hanson RL, Saxena R, Fowler S, Shuldiner AR, Knowler WC, Altshuler D, Florez JC: Common variants in 40 genes assessed for diabetes incidence and response to metformin and lifestyle intervention in the Diabetes Prevention Program. Diabetes 59:2672–2681, 2010 20682687
102 Tkac I, Klimcakova L, Javorsky M, Fabianova M, Schroner Z, Hermanova H, Babjakova E, Tkacova R: Pharmacogenomic association between a variant in SLC47A1 gene and therapeutic response to metformin in type 2 diabetes. Diabetes Obes Metab 15:189–191, 2013 22882994
103 GoDARTS and UKPDS Diabetes Pharmacogenetics Study Group; Wellcome Trust Case Control Consortium, Zhou K, Bellenguez C, Spencer CC, Bennett AJ, Coleman RL, Tavendale R, Hawley SA, Donnelly LA, Schofield C, Groves CJ, Burch L, Carr F, Strange A, Freeman C, Blackwell JM, Bramon E, Brown MA, Casas JP, Corvin A, Craddock N, Deloukas P, Dronov S, Duncanson A, Edkins S, Gray E, Hunt S, Jankowski J, Langford C, Markus HS, Mathew CG, Plomin R, Rautanen A, Sawcer SJ, Samani NJ, Trembath R, Viswanathan AC, Wood NW; MAGIC Investigators, Harries LW, Hattersley AT, Doney AS, Colhoun H, Morris AD, Sutherland C, Hardie DG, Peltonen L, McCarthy MI, Holman RR, Palmer CN, Donnelly P, Pearson ER: Common variants near ATM are associated with glycemic response to metformin in type 2 diabetes. Nat Genet 43:117–120, 2011 21186350
104 van Leeuwen N, Nijpels G, Becker ML, Deshmukh H, Zhou K, Stricker BH, Uitterlinden AG, Hofman A, van ’t Riet E, Palmer CN, Guigas B, Slagboom PE, Durrington P, Calle RA, Neil A, Hitman G, Livingstone SJ, Colhoun H, Holman RR, McCarthy MI, Dekker JM, ’t Hart LM, Pearson ER: A gene variant near ATM is significantly associated with metformin treatment response in type 2 diabetes: a replication and meta-analysis of five cohorts. Diabetologia 55:1971–1977, 2012 22453232
105 Florez JC, Jablonski KA, Taylor A, Mather K, Horton E, White NH, Barrett-Connor E, Knowler WC, Shuldiner AR, Pollin TI; Diabetes Prevention Program Research Group: The C allele of ATM rs11212617 does not associate with metformin response in the Diabetes Prevention Program. Diabetes Care 35:1864–1867, 2012 22751958
106 Zhou K, Donnelly L, Burch L, Tavendale R, Doney AS, Leese G, Hattersley AT, McCarthy MI, Morris AD, Lang CC, Palmer CN, Pearson ER: Loss-of-function CYP2C9 variants improve therapeutic response to sulfonylureas in type 2 diabetes: a Go-DARTS study. Clin Pharmacol Ther 87:52–56, 2010 19794412
107 Matthews DR, Hosker JP, Rudenski AS, Naylor BA, Treacher DF, Turner RC: Homeostasis model assessment: insulin resistance and beta-cell function from fasting plasma glucose and insulin concentrations in man. Diabetologia 28:412–419, 1985 3899825
108 Stumvoll M, Mitrakou A, Pimenta W, Jenssen T, Yki-Jarvinen H, Van Haeften T, Renn W, Gerich J: Use of the oral glucose tolerance test to assess insulin release and insulin sensitivity. Diabetes Care 23:295–301, 2000 10868854
109 Goodarzi MO, Langefeld CD, Xiang AH, Chen YD, Guo X, Hanley AJ, Raffel LJ, Kandeel F, Nadler JL, Buchanan TA, Norris JM, Fingerlin TE, Lorenzo C, Rewers MJ, Haffner SM, Bowden DW, Rich SS, Bergman RN, Rotter JI, Watanabe RM, Wagenknecht LE: Insulin sensitivity and insulin clearance are heritable and have strong genetic correlation in Mexican Americans. Obesity (Silver Spring) 22:1157–1164, 2014 24124113
110 Goodarzi MO, Guo X, Cui J, Jones MR, Haritunians T, Xiang AH, Chen YD, Taylor KD, Buchanan TA, Hsueh WA, Raffel LJ, Rotter JI: Systematic evaluation of validated type 2 diabetes and glycaemic trait loci for association with insulin clearance. Diabetologia 56:1282–1290, 2013 23494448
111 Zuk O, Schaffner SF, Samocha K, Do R, Hechter E, Kathiresan S, Daly MJ, Neale BM, Sunyaev SR, Lander ES: Searching for missing heritability: designing rare variant association studies. Proc Natl Acad Sci U S A 111:E455–E464, 2014 24443550
112 Manning AK, Lavalley M, Liu CT, Rice K, An P, Liu Y, Miljkovic I, Rasmussen-Torvik L, Harris TB, Province MA, Borecki IB, Florez JC, Meigs JB, Cupples LA, Dupuis J: Meta-analysis of gene-environment interaction: joint estimation of SNP and SNP x environment regression coefficients. Genet Epidemiol 35:11–18, 2011 21181894
113 Yang J, Loos RJ, Powell JE, Medland SE, Speliotes EK, Chasman DI, Rose LM, Thorleifsson G, Steinthorsdottir V, Magi R, Waite L, Smith AV, Yerges-Armstrong LM, Monda KL, Hadley D, Mahajan A, Li G, Kapur K, Vitart V, Huffman JE, Wang SR, Palmer C, Esko T, Fischer K, Zhao JH, Demirkan A, Isaacs A, Feitosa MF, Luan J, Heard-Costa NL, White C, Jackson AU, Preuss M, Ziegler A, Eriksson J, Kutalik Z, Frau F, Nolte IM, Van Vliet-Ostaptchouk JV, Hottenga JJ, Jacobs KB, Verweij N, Goel A, Medina-Gomez C, Estrada K, Bragg-Gresham JL, Sanna S, Sidore C, Tyrer J, Teumer A, Prokopenko I, Mangino M, Lindgren CM, Assimes TL, Shuldiner AR, Hui J, Beilby JP, McArdle WL, Hall P, Haritunians T, Zgaga L, Kolcic I, Polasek O, Zemunik T, Oostra BA, Junttila MJ, Gronberg H, Schreiber S, Peters A, Hicks AA, Stephens J, Foad NS, Laitinen J, Pouta A, Kaakinen M, Willemsen G, Vink JM, Wild SH, Navis G, Asselbergs FW, Homuth G, John U, Iribarren C, Harris T, Launer L, Gudnason V, O’Connell JR, Boerwinkle E, Cadby G, Palmer LJ, James AL, Musk AW, Ingelsson E, Psaty BM, Beckmann JS, Waeber G, Vollenweider P, Hayward C, Wright AF, Rudan I, Groop LC, Metspalu A, Tee Khaw K, van Duijn CM, Borecki IB, Province MA, Wareham NJ, Tardif JC, Huikuri HV, Cupples LA, Atwood LD, Fox CS, Boehnke M, Collins FS, Mohlke KL, Erdmann J, Schunkert H, Hengstenberg C, Stark K, Lorentzon M, Ohlsson C, Cusi D, Staessen JA, Van der Klauw MM, Pramstaller PP, Kathiresan S, Jolley JD, Ripatti S, Jarvelin MR, de Geus EJ, Boomsma DI, Penninx B, Wilson JF, Campbell H, Chanock SJ, van der Harst P, Hamsten A, Watkins H, Hofman A, Witteman JC, Zillikens MC, Uitterlinden AG, Rivadeneira F, Zillikens MC, Kiemeney LA, Vermeulen SH, Abecasis GR, Schlessinger D, Schipf S, Stumvoll M, Tonjes A, Spector TD, North KE, Lettre G, McCarthy MI, Berndt SI, Heath AC, Madden PA, Nyholt DR, Montgomery GW, Martin NG, McKnight B, Strachan DP, Hill WG, Snieder H, Ridker PM, Thorsteinsdottir U, Stefansson K, Frayling TM, Hirschhorn JN, Goddard ME, Visscher PM: FTO genotype is associated with phenotypic variability of body mass index. Nature 490:267–272, 2012 22982992
114 International Schizophrenia Consortium; Purcell SM, Wray NR, Stone JL, Visscher PM, O’Donovan MC, Sullivan PF, Sklar P: Common polygenic variation contributes to risk of schizophrenia and bipolar disorder. Nature 460:748–752, 2009 19571811
115 Yang J, Benyamin B, McEvoy BP, Gordon S, Henders AK, Nyholt DR, Madden PA, Heath AC, Martin NG, Montgomery GW, Goddard ME, Visscher PM: Common SNPs explain a large proportion of the heritability for human height. Nat Genet 42:565–569, 2010 20562875
116 Kong A, Steinthorsdottir V, Masson G, Thorleifsson G, Sulem P, Besenbacher S, Jonasdottir A, Sigurdsson A, Kristinsson KT, Frigge ML, Gylfason A, Olason PI, Gudjonsson SA, Sverrisson S, Stacey SN, Sigurgeirsson B, Benediktsdottir KR, Sigurdsson H, Jonsson T, Benediktsson R, Olafsson JH, Johannsson OT, Hreidarsson AB, Sigurdsson G; DIAGRAM Consortium, Ferguson-Smith AC, Gudbjartsson DF, Thorsteinsdottir U, Stefansson K: Parental origin of sequence variants associated with complex diseases. Nature 462:868–874, 2009 20016592
117 Hamming KS, Soliman D, Matemisz LC, Niazi O, Lang Y, Gloyn AL, Light PE: Coexpression of the type 2 diabetes susceptibility gene variants KCNJ11 E23K and ABCC8 S1369A alter the ATP and sulfonylurea sensitivities of the ATP-sensitive K(+) channel. Diabetes 58:2419–2424, 2009 19587354
118 Edwards SL, Beesley J, French JD, Dunning AM: Beyond GWASs: illuminating the dark road from association to function. Am J Hum Genet 93:779–797, 2013 24210251
119 GTEx Consortium: Human genomics. The Genotype-Tissue Expression (GTEx) pilot analysis: multitissue gene regulation in humans. Science 348:648–660, 2015 25954001
120 Florez JC, Jablonski KA, Bayley N, Pollin TI, de Bakker PI, Shuldiner AR, Knowler WC, Nathan DM, Altshuler D; Diabetes Prevention Program Research Group: TCF7L2 polymorphisms and progression to diabetes in the Diabetes Prevention Program. N Engl J Med 355:241–250, 2006 16855264
121 Lyssenko V, Lupi R, Marchetti P, Del Guerra S, Orho-Melander M, Almgren P, Sjogren M, Ling C, Eriksson KF, Lethagen AL, Mancarella R, Berglund G, Tuomi T, Nilsson P, Del Prato S, Groop L: Mechanisms by which common variants in the TCF7L2 gene increase risk of type 2 diabetes. J Clin Invest 117:2155–2163, 2007 17671651
122 Gaulton KJ, Nammo T, Pasquali L, Simon JM, Giresi PG, Fogarty MP, Panhuis TM, Mieczkowski P, Secchi A, Bosco D, Berney T, Montanya E, Mohlke KL, Lieb JD, Ferrer J: A map of open chromatin in human pancreatic islets. Nat Genet 42:255–259, 2010 20118932
123 Small KS, Hedman AK, Grundberg E, Nica AC, Thorleifsson G, Kong A, Thorsteindottir U, Shin SY, Richards HB; GIANT Consortium; MAGIC Investigators; DIAGRAM Consortium, Soranzo N, Ahmadi KR, Lindgren CM, Stefansson K, Dermitzakis ET, Deloukas P, Spector TD, McCarthy MI; MuTHER Consortium: Identification of an imprinted master trans regulator at the KLF14 locus related to multiple metabolic phenotypes. Nat Genet 43:561–564, 2011 21572415
124 Bouatia-Naji N, Bonnefond A, Baerenwald DA, Marchand M, Bugliani M, Marchetti P, Pattou F, Printz RL, Flemming BP, Umunakwe OC, Conley NL, Vaxillaire M, Lantieri O, Balkau B, Marre M, Levy-Marchal C, Elliott P, Jarvelin MR, Meyre D, Dina C, Oeser JK, Froguel P, O’Brien RM: Genetic and functional assessment of the role of the rs13431652-A and rs573225-A alleles in the G6PC2 promoter that are strongly associated with elevated fasting glucose levels. Diabetes 59:2662–2671, 2010 20622168
125 van de Bunt M, Gloyn AL: From genetic association to molecular mechanism. Curr Diab Rep 10:452–466, 2010 20878272
126 Groop L, Pociot F: Genetics of diabetes—are we missing the genes or the disease? Mol Cell Endocrinol 382:726–739, 2014 23587769
127 Florez JC, Burtt N, de Bakker PI, Almgren P, Tuomi T, Holmkvist J, Gaudet D, Hudson TJ, Schaffner SF, Daly MJ, Hirschhorn JN, Groop L, Altshuler D: Haplotype structure and genotype-phenotype correlations of the sulfonylurea receptor and the islet ATP-sensitive potassium channel gene region. Diabetes 53:1360–1368, 2004 15111507
128 Rung J, Cauchi S, Albrechtsen A, Shen L, Rocheleau G, Cavalcanti-Proenca C, Bacot F, Balkau B, Belisle A, Borch-Johnsen K, Charpentier G, Dina C, Durand E, Elliott P, Hadjadj S, Jarvelin MR, Laitinen J, Lauritzen T, Marre M, Mazur A, Meyre D, Montpetit A, Pisinger C, Posner B, Poulsen P, Pouta A, Prentki M, Ribel-Madsen R, Ruokonen A, Sandbaek A, Serre D, Tichet J, Vaxillaire M, Wojtaszewski JF, Vaag A, Hansen T, Polychronakos C, Pedersen O, Froguel P, Sladek R: Genetic variant near IRS1 is associated with type 2 diabetes, insulin resistance and hyperinsulinemia. Nat Genet 41:1110–1115, 2009 19734900
129 Qi L, Cornelis MC, Kraft P, Stanya KJ, Linda Kao WH, Pankow JS, Dupuis J, Florez JC, Fox CS, Pare G, Sun Q, Girman CJ, Laurie CC, Mirel DB, Manolio TA, Chasman DI, Boerwinkle E, Ridker PM, Hunter DJ, Meigs JB, Lee CH, Hu FB, van Dam RM; Meta-Analyses of Glucose and Insulin-related traits Consortium (MAGIC); DIAbetes Genetics Replication And Meta-analysis (DIAGRAM) Consortium: Genetic variants at 2q24 are associated with susceptibility to type 2 diabetes. Hum Mol Genet 19:2706–2715, 2010 20418489
130 Sandhu MS, Weedon MN, Fawcett KA, Wasson J, Debenham SL, Daly A, Lango H, Frayling TM, Neumann RJ, Sherva R, Blech I, Pharoah PD, Palmer CNA, Kimber C, Tavendale R, Morris AD, McCarthy MI, Walker M, Hitman G, Glaser B, Permutt MA, Hattersley AT, Wareham NJ, Barroso I: Common variants in WFS1 confer risk of type 2 diabetes. Nat Genet 39:951–953, 2007 17603484
131 Frayling TM, Timpson NJ, Weedon MN, Zeggini E, Freathy RM, Lindgren CM, Perry JR, Elliott KS, Lango H, Rayner NW, Shields B, Harries LW, Barrett JC, Ellard S, Groves CJ, Knight B, Patch AM, Ness AR, Ebrahim S, Lawlor DA, Ring SM, Ben-Shlomo Y, Jarvelin MR, Sovio U, Bennett AJ, Melzer D, Ferrucci L, Loos RJ, Barroso I, Wareham NJ, Karpe F, Owen KR, Cardon LR, Walker M, Hitman GA, Palmer CN, Doney AS, Morris AD, Smith GD, Hattersley AT, McCarthy MI: A common variant in the FTO gene is associated with body mass index and predisposes to childhood and adult obesity. Science 316:889–894, 2007 17434869
132 Winckler W, Weedon MN, Graham RR, McCarroll SA, Purcell S, Almgren P, Tuomi T, Gaudet D, Bostrom KB, Walker M, Hitman G, Hattersley AT, McCarthy MI, Ardlie KG, Hirschhorn JN, Daly MJ, Frayling TM, Groop L, Altshuler D: Evaluation of common variants in the six known maturity-onset diabetes of the young (MODY) genes for association with type 2 diabetes. Diabetes 56:685–693, 2007 17327436
133 Gudmundsson J, Sulem P, Steinthorsdottir V, Bergthorsson JT, Thorleifsson G, Manolescu A, Rafnar T, Gudbjartsson D, Agnarsson BA, Baker A, Sigurdsson A, Benediktsdottir KR, Jakobsdottir M, Blondal T, Stacey SN, Helgason A, Gunnarsdottir S, Olafsdottir A, Kristinsson KT, Birgisdottir B, Ghosh S, Thorlacius S, Magnusdottir D, Stefansdottir G, Kristjansson K, Bagger Y, Wilensky RL, Reilly MP, Morris AD, Kimber CH, Adeyemo A, Chen Y, Zhou J, So WY, Tong PC, Ng MC, Hansen T, Andersen G, Borch-Johnsen K, Jorgensen T, Tres A, Fuertes F, Ruiz-Echarri M, Asin L, Saez B, van Boven E, Klaver S, Swinkels DW, Aben KK, Graif T, Cashy J, Suarez BK, van Vierssen Trip O, Frigge ML, Ober C, Hofker MH, Wijmenga C, Christiansen C, Rader DJ, Palmer CN, Rotimi C, Chan JC, Pedersen O, Sigurdsson G, Benediktsson R, Jonsson E, Einarsson GV, Mayordomo JI, Catalona WJ, Kiemeney LA, Barkardottir RB, Gulcher JR, Thorsteinsdottir U, Kong A, Stefansson K: Two variants on chromosome 17 confer prostate cancer risk, and the one in TCF2 protects against type 2 diabetes. Nat Genet 39:977–983, 2007 17603485
134 Perry JR, Voight BF, Yengo L, Amin N, Dupuis J, Ganser M, Grallert H, Navarro P, Li M, Qi L, Steinthorsdottir V, Scott RA, Almgren P, Arking DE, Aulchenko Y, Balkau B, Benediktsson R, Bergman RN, Boerwinkle E, Bonnycastle L, Burtt NP, Campbell H, Charpentier G, Collins FS, Gieger C, Green T, Hadjadj S, Hattersley AT, Herder C, Hofman A, Johnson AD, Kottgen A, Kraft P, Labrune Y, Langenberg C, Manning AK, Mohlke KL, Morris AP, Oostra B, Pankow J, Petersen AK, Pramstaller PP, Prokopenko I, Rathmann W, Rayner W, Roden M, Rudan I, Rybin D, Scott LJ, Sigurdsson G, Sladek R, Thorleifsson G, Thorsteinsdottir U, Tuomilehto J, Uitterlinden AG, Vivequin S, Weedon MN, Wright AF; MAGIC; DIAGRAM Consortium; GIANT Consortium, Hu FB, Illig T, Kao L, Meigs JB, Wilson JF, Stefansson K, van Duijn C, Altschuler D, Morris AD, Boehnke M, McCarthy MI, Froguel P, Palmer CN, Wareham NJ, Groop L, Frayling TM, Cauchi S: Stratifying type 2 diabetes cases by BMI identifies genetic risk variants in LAMA1 and enrichment for risk variants in lean compared to obese cases. PLoS Genet 8:e1002741, 2012 22693455
135 Chen P, Takeuchi F, Lee JY, Li H, Wu JY, Liang J, Long J, Tabara Y, Goodarzi MO, Pereira MA, Kim YJ, Go MJ, Stram DO, Vithana E, Khor CC, Liu J, Liao J, Ye X, Wang Y, Lu L, Young TL, Lee J, Thai AC, Cheng CY, van Dam RM, Friedlander Y, Heng CK, Koh WP, Chen CH, Chang LC, Pan WH, Qi Q, Isono M, Zheng W, Cai Q, Gao Y, Yamamoto K, Ohnaka K, Takayanagi R, Kita Y, Ueshima H, Hsiung CA, Cui J, Sheu WH, Rotter JI, Chen YD, Hsu C, Okada Y, Kubo M, Takahashi A, Tanaka T, van Rooij FJ, Ganesh SK, Huang J, Huang T, Yuan J, Hwang JY; CHARGE Hematology Working Group, Gross MD, Assimes TL, Miki T, Shu XO, Qi L, Chen YT, Lin X, Aung T, Wong TY, Teo YY, Kim BJ, Kato N, Tai ES: Multiple nonglycemic genomic loci are newly associated with blood level of glycated hemoglobin in East Asians. Diabetes 63:2551–2562, 2014 24647736
136 Hwang JY, Sim X, Wu Y, Liang J, Tabara Y, Hu C, Hara K, Tam CH, Cai Q, Zhao Q, Jee S, Takeuchi F, Go MJ, Ong RT, Ohkubo T, Kim YJ, Zhang R, Yamauchi T, So WY, Long J, Gu D, Lee NR, Kim S, Katsuya T, Oh JH, Liu J, Umemura S, Kim YJ, Jiang F, Maeda S, Chan JC, Lu W, Hixson JE, Adair LS, Jung KJ, Nabika T, Bae JB, Lee MH, Seielstad M, Young TL, Teo YY, Kita Y, Takashima N, Osawa H, Lee SH, Shin MH, Shin DH, Choi BY, Shi J, Gao YT, Xiang YB, Zheng W, Kato N, Yoon M, He J, Shu XO, Ma RC, Kadowaki T, Jia W, Miki T, Qi L, Tai ES, Mohlke KL, Han BG, Cho YS, Kim BJ: Genome-wide association meta-analysis identifies novel variants associated with fasting plasma glucose in East Asians. Diabetes 64:291–298, 2015 25187374
137 Kim YJ, Go MJ, Hu C, Hong CB, Kim YK, Lee JY, Hwang JY, Oh JH, Kim DJ, Kim NH, Kim S, Hong EJ, Kim JH, Min H, Kim Y, Zhang R, Jia W, Okada Y, Takahashi A, Kubo M, Tanaka T, Kamatani N, Matsuda K; MAGIC Consortium, Park T, Oh B, Kimm K, Kang D, Shin C, Cho NH, Kim HL, Han BG, Lee JY, Cho YS: Large-scale genome-wide association studies in East Asians identify new genetic loci influencing metabolic traits. Nat Genet 43:990–995, 2011 21909109
138 Ryu J, Lee C: Association of glycosylated hemoglobin with the gene encoding CDKAL1 in the Korean Association Resource (KARE) study. Hum Mutat 33:655–659, 2012 22290723
139 Horikoshi M, Magi R, van de Bunt M, Surakka I, Sarin AP, Mahajan A, Marullo L, Thorleifsson G, Hagg S, Hottenga JJ, Ladenvall C, Ried JS, Winkler TW, Willems SM, Pervjakova N, Esko T, Beekman M, Nelson CP, Willenborg C, Wiltshire S, Ferreira T, Fernandez J, Gaulton KJ, Steinthorsdottir V, Hamsten A, Magnusson PK, Willemsen G, Milaneschi Y, Robertson NR, Groves CJ, Bennett AJ, Lehtimki T, Viikari JS, Rung J, Lyssenko V, Perola M, Heid IM, Herder C, Grallert H, Muller-Nurasyid M, Roden M, Hypponen E, Isaacs A, van Leeuwen EM, Karssen LC, Mihailov E, Houwing-Duistermaat JJ, de Craen AJ, Deelen J, Havulinna AS, Blades M, Hengstenberg C, Erdmann J, Schunkert H, Kaprio J, Tobin MD, Samani NJ, Lind L, Salomaa V, Lindgren CM, Slagboom PE, Metspalu A, van Duijn CM, Eriksson JG, Peters A, Gieger C, Jula A, Groop L, Raitakari OT, Power C, Penninx BW, de Geus E, Smit JH, Boomsma DI, Pedersen NL, Ingelsson E, Thorsteinsdottir U, Stefansson K, Ripatti S, Prokopenko I, McCarthy MI, Morris AP; ENGAGE Consortium: Discovery and fine-mapping of glycaemic and obesity-related trait loci using high-density imputation. PLoS Genet 11:e1005230, 2015 26132169
140 Chen G, Bentley A, Adeyemo A, Shriner D, Zhou J, Doumatey A, Huang H, Ramos E, Erdos M, Gerry N, Herbert A, Christman M, Rotimi C: Genome-wide association study identifies novel loci association with fasting insulin and insulin resistance in African Americans. Hum Mol Genet 21:4530–4536, 2012 22791750
141 Bouatia-Naji N, Bonnefond A, Cavalcanti-Proenca C, Sparso T, Holmkvist J, Marchand M, Delplanque J, Lobbens S, Rocheleau G, Durand E, De Graeve F, Chevre JC, Borch-Johnsen K, Hartikainen AL, Ruokonen A, Tichet J, Marre M, Weill J, Heude B, Tauber M, Lemaire K, Schuit F, Elliott P, Jorgensen T, Charpentier G, Hadjadj S, Cauchi S, Vaxillaire M, Sladek R, Visvikis-Siest S, Balkau B, Levy-Marchal C, Pattou F, Meyre D, Blakemore AI, Jarvelin MR, Walley AJ, Hansen T, Dina C, Pedersen O, Froguel P: A variant near MTNR1B is associated with increased fasting plasma glucose levels and type 2 diabetes risk. Nat Genet 41:89–94, 2009 19060909
142 Palmer ND, Goodarzi MO, Langefeld CD, Wang N, Guo X, Taylor KD, Fingerlin TE, Norris JM, Buchanan TA, Xiang AH, Haritunians T, Ziegler JT, Williams AH, Stefanovski D, Cui J, Mackay AW, Henkin LF, Bergman RN, Gao X, Gauderman J, Varma R, Hanis CL, Cox NJ, Highland HM, Below JE, Williams AL, Burtt NP, Aguilar-Salinas CA, Huerta-Chagoya A, Gonzalez-Villalpando C, Orozco L, Haiman CA, Tsai MY, Johnson WC, Yao J, Rasmussen-Torvik L, Pankow J, Snively B, Jackson RD, Liu S, Nadler JL, Kandeel F, Chen YD, Bowden DW, Rich SS, Raffel LJ, Rotter JI, Watanabe RM, Wagenknecht LE: Genetic variants associated with quantitative glucose homeostasis traits translate to type 2 diabetes in Mexican Americans: the GUARDIAN (Genetics Underlying Diabetes in Hispanics) Consortium. Diabetes 64:1853–1866, 2015 25524916
143 Go MJ, Hwang JY, Kim YJ, Hee Oh J, Kim YJ, Heon Kwak S, Soo Park K, Lee J, Kim BJ, Han BG, Cho MC, Cho YS, Lee JY: New susceptibility loci in MYL2, C12orf51 and OAS1 associated with 1-h plasma glucose as predisposing risk factors for type 2 diabetes in the Korean population. J Hum Genet 58:362–365, 2013 23575436