# APPENDIX 1 Conversions

A1c, Glycated^*^ Hemoglobin

% | mmol/mol^†^
3.0 | 9
3.1 | 10
3.2 | 11
3.3 | 13
3.4 | 14
3.5 | 15
3.6 | 16
3.7 | 17
3.8 | 18
3.9 | 19
4.0 | 20
4.1 | 21
4.2 | 22
4.3 | 23
4.4 | 25
4.5 | 26
4.6 | 27
4.7 | 28
4.8 | 29
4.9 | 30
5.0 | 31
5.1 | 32
5.2 | 33
5.3 | 34
5.4 | 36
5.5 | 37
5.6 | 38
5.7 | 39
5.8 | 40
5.9 | 41
6.0 | 42
6.1 | 43
6.2 | 44
6.3 | 45
6.4 | 46
6.5 | 48
6.6 | 49
6.7 | 50
6.8 | 51
6.9 | 52
7.0 | 53
7.1 | 54
7.2 | 55
7.3 | 56
7.4 | 57
7.5 | 58
7.6 | 60
7.7 | 61
7.8 | 62
7.9 | 63
8.0 | 64
8.1 | 65
8.2 | 66
8.3 | 67
8.4 | 68
8.5 | 69
8.6 | 70
8.7 | 72
8.8 | 73
8.9 | 74
9.0 | 75
9.1 | 76
9.2 | 77
9.3 | 78
9.4 | 79
9.5 | 80
9.6 | 81
9.7 | 83
9.8 | 84
9.9 | 85
10.0 | 86
10.1 | 87
10.2 | 88
10.3 | 89
10.4 | 90
10.5 | 91
10.6 | 92
10.7 | 93
10.8 | 95
10.9 | 96
11.0 | 97
11.5 | 102
12.0 | 108
12.5 | 113
13.0 | 119
13.5 | 124
14.0 | 130
14.5 | 135
15.0 | 140
15.5 | 146
16.0 | 151
16.5 | 157
17.0 | 162
17.5 | 168
18.0 | 173
18.5 | 179
19.0 | 184
19.5 | 190
20.0 | 195

* The term “glycated” hemoglobin is used interchangeably with “glycosylated” in the literature and in Diabetes in America, 3rd Edition, though glycated is considered more correct biochemically.

† International System of Units (SI) values

Conversion: (% × 10.93) – 23.50 = mmol/mol

SOURCE: Reference 1

Glucose

mg/dL | mmol/L^*^
2 | 0.11
5 | 0.28
10 | 0.56
15 | 0.83
20 | 1.11
25 | 1.39
30 | 1.67
35 | 1.94
40 | 2.22
45 | 2.50
50 | 2.78
55 | 3.05
60 | 3.33
65 | 3.61
70 | 3.89
71 | 3.94
72 | 4.00
73 | 4.05
74 | 4.11
75 | 4.16
76 | 4.22
77 | 4.27
78 | 4.33
79 | 4.38
80 | 4.44
81 | 4.50
82 | 4.55
83 | 4.61
84 | 4.66
85 | 4.72
86 | 4.77
87 | 4.83
88 | 4.88
89 | 4.94
90 | 5.00
91 | 5.05
92 | 5.11
93 | 5.16
94 | 5.22
95 | 5.27
96 | 5.33
97 | 5.38
98 | 5.44
99 | 5.49
100 | 5.55
101 | 5.61
102 | 5.66
103 | 5.72
104 | 5.77
105 | 5.83
106 | 5.88
107 | 5.94
108 | 5.99
109 | 6.05
110 | 6.11
111 | 6.16
112 | 6.22
113 | 6.27
114 | 6.33
115 | 6.38
116 | 6.44
117 | 6.49
118 | 6.55
119 | 6.60
120 | 6.66
121 | 6.72
122 | 6.77
123 | 6.83
124 | 6.88
125 | 6.94
126 | 6.99
127 | 7.05
128 | 7.10
129 | 7.16
130 | 7.22
131 | 7.27
132 | 7.33
133 | 7.38
134 | 7.44
135 | 7.49
136 | 7.55
137 | 7.60
138 | 7.66
139 | 7.71
140 | 7.77
141 | 7.83
142 | 7.88
143 | 7.94
144 | 7.99
145 | 8.05
146 | 8.10
147 | 8.16
148 | 8.21
149 | 8.27
150 | 8.33
151 | 8.38
152 | 8.44
153 | 8.49
154 | 8.55
155 | 8.60
156 | 8.66
157 | 8.71
158 | 8.77
159 | 8.82
160 | 8.88
161 | 8.94
162 | 8.99
163 | 9.05
164 | 9.10
165 | 9.16
166 | 9.21
167 | 9.27
168 | 9.32
169 | 9.38
170 | 9.44
171 | 9.49
172 | 9.55
173 | 9.60
174 | 9.66
175 | 9.71
176 | 9.77
177 | 9.82
178 | 9.88
179 | 9.93
180 | 10.00
181 | 10.05
182 | 10.10
183 | 10.16
184 | 10.21
185 | 10.27
186 | 10.32
187 | 10.38
188 | 10.43
189 | 10.49
190 | 10.55
191 | 10.60
192 | 10.66
193 | 10.71
194 | 10.77
195 | 10.82
196 | 10.88
197 | 10.93
198 | 10.99
199 | 11.04
200 | 11.10
205 | 11.38
210 | 11.66
215 | 11.93
220 | 12.21
225 | 12.49
230 | 12.77
235 | 13.04
240 | 13.32
245 | 13.60
250 | 13.88
255 | 14.15
260 | 14.43
265 | 14.71
270 | 14.99
275 | 15.26
280 | 15.54
285 | 15.82
290 | 16.10
295 | 16.37
300 | 16.65
320 | 17.76
340 | 18.87
360 | 19.98
380 | 21.09
400 | 22.20
420 | 23.31
440 | 24.42
460 | 25.53
480 | 26.64
500 | 27.75
550 | 30.53
600 | 33.30
650 | 36.10
700 | 38.85
750 | 41.63

Conversion: mg/dL × 0.0555 = mmol/L

* International System of Units (SI) values

SOURCE: Reference 2

Insulin

μIU/mL | pmol/L^*^
1 | 6
2 | 12
3 | 18
4 | 24
5 | 30
6 | 36
7 | 42
8 | 48
9 | 54
10 | 60
11 | 66
12 | 72
13 | 78
14 | 84
15 | 90
16 | 96
17 | 102
18 | 108
19 | 114
20 | 120
21 | 126
22 | 132
23 | 138
24 | 144
25 | 150
26 | 156
27 | 162
28 | 168
29 | 174
30 | 180

Conversion: μIU/mL × 6 = pmol/L

* International System of Units (SI) values

SOURCE: Reference 2

Cholesterol (HDL, LDL, TOTAL)

mg/dL | mmol/L^*^
4.0 | 0.10
5.0 | 0.13
10 | 0.26
15 | 0.39
20 | 0.52
25 | 0.65
30 | 0.78
35 | 0.91
40 | 1.04
45 | 1.17
50 | 1.30
55 | 1.42
60 | 1.55
65 | 1.68
70 | 1.81
75 | 1.94
80 | 2.07
85 | 2.20
90 | 2.33
95 | 2.46
100 | 2.59
105 | 2.72
110 | 2.85
115 | 2.98
120 | 3.11
125 | 3.24
130 | 3.37
135 | 3.50
140 | 3.63
145 | 3.76
150 | 3.89
155 | 4.01
160 | 4.14
165 | 4.27
170 | 4.40
175 | 4.53
180 | 4.66
185 | 4.79
190 | 4.92
195 | 5.05
200 | 5.18
210 | 5.44
220 | 5.70
230 | 5.96
240 | 6.22
250 | 6.48
260 | 6.73
270 | 6.99
280 | 7.25
290 | 7.51
300 | 7.77

Conversion: mg/dL × 0.0259 = mmol/L

* International System of Units (SI) values

SOURCE: Reference 2

Triglycerides

mg/dL | mmol/L^*^
100 | 1.13
105 | 1.19
110 | 1.24
115 | 1.30
120 | 1.36
125 | 1.41
130 | 1.47
135 | 1.53
140 | 1.58
145 | 1.64
150 | 1.70
155 | 1.75
160 | 1.81
165 | 1.86
170 | 1.92
175 | 1.98
180 | 2.03
185 | 2.09
190 | 2.15
195 | 2.20
200 | 2.26

Conversion: mg/dL × 0.0113 = mmol/L

* International System of Units (SI) values

SOURCE: Reference 2

C-Peptide

ng/mL | nmol/L^*^
0.1 | 0.03
0.2 | 0.07
0.3 | 0.10
0.4 | 0.13
0.5 | 0.17
0.6 | 0.20
0.7 | 0.23
0.8 | 0.27
0.9 | 0.30
1.0 | 0.33
1.5 | 0.50
2.0 | 0.67
2.5 | 0.83
3.0 | 1.00
3.5 | 1.17

Conversion: ng/mL × 0.333 = nmol/L

* International System of Units (SI) values

SOURCE: Reference 2

## References

1 NGSP: harmonizing hemoglobin A1c testing: convert between NGSP, IFCC and eAG [article online], 2010. Available from http://www.ngsp.org/convert1.asp. Accessed 20 September 2016
2 Society for Biomedical Diabetes Research: SI unit conversion calculator [article online], 2015. Available from http://www.soc-bdr.org/content/rds/authors/unit_tables_conversions_and_genetic_dictionaries/e5196/index_en.html. Accessed 20 September 2016