# 3CL enzymatic activity

Target Category | Viral replication
Target | SARS-CoV-2 3CL protease activity
Assay Type | Biochemical
Cell Line | N/A
Detection Type | Fluorescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

SARS-CoV-2 contain a positive-sense single stranded RNA genome. Upon cell entry, the genome is translated into polyproteins that must be cleaved into individual proteins in order to function. These cleavage events are carried out a papain-like protease 3CL (also called Mpro). Inhibition of polyprotein cleavage would block viral replication. 3CL represents an attractive target for drug development due to cleavage specificities that are unique and highly divergent from human sequences. This SARS-CoV-2 3CL biochemical assay measures the ability of compounds to inhibit recombinant 3CL cleavage of a fluorescently labeled peptide substrate.

## Protocol

1 Dispense 2 μL 3CL to 1536 well plate (square well, high base, black plate, solid bottom, non-sterile; Cat #: 782076, Greiner Bio-one) by Multidrop Combi disperser (Thermo Fisher); skip columns 1 and 2 which were dispensed 2 μL assay buffer only.Note: 3CL Protease (Mpro), MBP-tag (SARS-CoV-2) (Cat #: 100707, BPS Bioscience) in 3CL protease assay buffer (Cat# 79956, BPS Bioscience).
2 Transfer 23 nL library compounds in DMSO into assay plate using an automated pintool workstation (WAKO Scientific Solutions), and spin 2 min at 1000 rpm (100×g) followed by incubation of 30 min at RT.
3 Dispense 2 μL SARS-CoV-2 3CL substrate to the whole assay plate.Note: 3CL Protease Substrate (Cat# 79952, BPS Bioscience)
4 Centrifuge the assay plate at 1000 rpm for 2 min (100×g), and incubate for 3 h at RT.
5 Read on PHERAstar plate reader (BMG Labtech).

Note: Fluorescence read at excitation and emission wavelengths of 340 nm and 460 nm, respectively.

## Normalization/Assay interpretation

Data was normalized to enzyme activity in presence of DMSO, set as 0%, and in absence of enzyme, set as -100% inhibition. The resulting percent of inhibition data were fitted to a sigmoidal dose response curve using four-parameter Hill equation.