# TMPRSS2 enzymatic activity

Target Category | Viral Entry
Target | TMPRSS2 enzymatic activity
Assay Type | Biochemical
Cell Line | N/A
Detection Type | Fluorescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

Transmembrane protease serine 2 (TMPRSS2) is a type II transmembrane serine protease that is expressed and self-cleaved from the surface of epithelial cells in a variety of tissues. Although the biological function of TMPRSS2 remains unclear, it is believed to serve as an initiator protease in the extracellular matrix (ECM). Regulated through the androgen receptor, TMPRSS2 is most notable as a genetic translocation fusion with the ERG transcription factor in many prostate cancers. However, TMPRSS2 has more recently been shown to play a role in SARS-CoV2 S (spike) protein priming following ACE2 binding, contributing to viral-host membrane fusion and subsequent infection. Previously, in vivo mouse models for SARS-CoV and MERS-CoV with a TMPRSS2 gene knockout caused a reduction in lung pathology after viral infection while not seeing any effect on development or survival, which supports TMPRSS2 as a suitable target for therapeutic development. This enzymatic assay will serve to monitor activity of human TMPRSS2 and facilitate detection of small molecules with the potential to disrupt endogenous enzyme function.

## Protocol

Assay ready plates were prepared using an Echo 650 series acoustic dispenser (Labcyte) in black, solid bottom, medium-binding 1536-well plates (Greiner, Cat # 782076). Recombinant human TMPRSS2 protein (N-terminal His-tagged TMPRSS2, amino acid 106-492, produced in yeast; Cat #: CSB-YP023924HU, Cusabio) and fluorescent-labeled peptide substrate (Boc-Gln-Ala-Arg-AMC, Cat #: I-1550, Cas#: 201849-55-0 Bachem) were used to monitor TMPRSS2 enzymatic activity.

1 Dispense 20 nL of inhibitor (250X) dissolved in DMSO to columns 5 – 48.
2 Dispense 20 nL fluorescent peptide substrate (250X Boc-Gln-Ala-Arg-AMC, 10 µM) dissolved in DMSO across the plate.
3 Dilute TMPRSS2 (32X His-TMPRSS2 (106-492); 5.6 µM, Cat #: CSB-YP023924HU, Cusabio) in 50 mM Tris-HCl; pH8.0 (Cat # 15568025), 150nM NaCl (Cat # S6546-1L), 0.01% Tween-20 (Cat # P1379-25ML).
4 Dispense 5 µL of diluted TMPRSS2 solution to columns 2 – 48. To column 1, dispense 5 µL assay buffer only.
5 Incubate at RT for 60 min
6 Read on PHERAstar FSX (BMG Labtech); read settings, Fluorescence Instensity Module (340 nm excitation, 440 nm emission) (Cat #: FI340440, BMG Labtech)

## Normalization/Assay interpretation

Data is normalized to a high-signal vehicle control (TMPRSS2 + Peptide + DMSO) and a low-signal control (TMPRSS2 + Peptide + Nafamostat at 1 µM). A high signal, approaching zero on a normalized plot, indicates no inhibition of TMPRSS2 activity. A low signal, approaching -100 on a normalized plot), is equivalent to the low-signal control fluorescence and no detectable enzymatic activity.