# Spike-ACE2 protein-protein interaction (QD)

Target Category | Viral Entry
Target | SARS-CoV-2 Spike ACE2 interaction
Assay Type | Proximity
Cell Line | N/A
Detection Type | High-content imaging
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

Under development

## Protocol

Under development

## Normalization/Assay interpretation

Under development