# Spike-ACE2 protein-protein interaction (TruHit Counterscreen)

Target Category | Counterscreen
Target | Counterscreen
Assay Type | Proximity
Cell Line | N/A
Detection Type | AlphaLISA
Date Screened | 2020-05-08
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

TruHits is a counterscreen used to determine if agents tested in qHTS interfere with the AlphaLISA readout. While many AlphaLISA assays use a sandwich approach to determine if two labeled components interact, TruHits simply uses two beads designed to directly interact via Biotin-Streptavidin interactions. Common interfering agents are oxygen scavengers or molecules with spectral properties sensitive to the 600-700 nm wavelengths used in AlphaLISA. This counterscreen is used to verify that activity observed in a qHTS AlphaLISA assay is not due to interference with the assay system itself.

## Protocol

Followed manufactures recommended protocol for use of bead control set to identify AlphaLISA false positive and interfering compounds.

1 Dispense 3 µL ACE2-His-Avi (2X Biotin-BSA Acceptor beads (0.01 mg/mL, TruHits kit Cat #: 6760627, PerkinElmer) in PBS (Cat #: 10010-031, ThermoFisher) + 0.05 mg/mL BSA (Cat #: BP1600-1, Fisher Scientific)) into 1536-well plate square well, high base, white plate, solid bottom, non-sterile, non-treated; Cat # EWB010000A, Aurora); skip column 2
2 Incubate at RT for 30 min, shaking at 200 rpm on orbital plate shaker
3 Dispense 3 µL Streptavidin Donor beads, skip column 3 (2X Streptavidin Donor beads (0.01 mg/mL, TruHits kit Cat #: 6760627, PerkinElmer) in PBS (Cat #: 10010-031, ThermoFisher) in PBS + 0.05 mg/mL BSA)
4 Incubate at RT for 30 min, shaking at 200 rpm on orbital plate shaker
5 Read on PHERAstar FSX (BMG Labtech); Fastest read settings, AlphaLISA Module (680 nm excitation, 615 nm emission) (Cat #: 1802H1, BMG Labtech)

## Normalization/Assay interpretation

Data is normalized to a high-signal vehicle control (Streptavidin donor beads + Biotin acceptor beads + DMSO) and a low-signal control (Streptavidin donor beads + DMSO). An internal ‘assay performance’ control is also included on each plate, generated using a serial dilution of biotin. A high signal, approaching zero on a normalized plot, indicates no deviation between the components of the AlphaLISA system. A low signal, approaching -100 on a normalized plot), suggests potential interference of the AlphaLISA assay.