# Spike-ACE2 protein-protein interaction (AlphaLISA)

Target Category | Viral Entry
Target | Human ACE2 receptor protein
Assay Type | Proximity
Cell Line | N/A
Detection Type | AlphaLISA
Date Screened | 2020-05-05
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

Surface ACE2 receptor protein has been shown to be the primary host factor recognized and targeted by SARS-CoV-2 virions. This binding event between SARS-CoV-2 Spike protein and host ACE2 initiates binding of the viral capsid and eventually leads to viral entry in host cells. Disrupting of the Spike protein-ACE2 interaction may cripple the ability of SARS-CoV-2 virions to infect host cells. Therefore, we developed a proximity assay using AlphaLISA technology to determine the ability of therapeutics (small molecules, antibodies, peptides, etc.) to disrupt this important protein-protein interaction.

## Protocol

Assay ready plates were prepared using an Echo 650 series acoustic dispenser (Labcyte). Recombinant human ACE2 receptor protein (ACE2-His-Avi, Cat #: AC2H82E6, Acro Biosystems) and recombinant SARS-CoV-2 spike protein (RBD-Fc, Cat #: 40592-V02H, Sino Biologicals) were used to model the ACE2-Spike protein interaction.

1 Dispense 2 µL ACE2-His-Avi (4X ACE2-His-Avi (16 nM, Cat #: AC2-H82E6, Acro Biosystems)) in PBS (Cat #: 10010-031, ThermoFisher) + 0.05 mg/mL BSA (Cat : BP1600-1,Fisher Scientific).
2 Incubate at RT for 30 min, shaking at 200 rpm on orbital plate shaker
3 Dispense 2 µL RBD-Fc, skip column 3 (4X RBD-Fc (16 nM, Cat #: 40592-V02H, Sino Biological) in PBS + 0.05 mg/mL BSA)
4 Incubate at RT for 30 min, shaking at 200 rpm on orbital plate shaker
5 Dispense 4 µL of AlphaLISA Donor/Acceptor beads, skip column 1 (2X Protein A acceptor beads (20 µg/mL, Cat #: AL101M, PerkinElmer), 2X Strep donor beads (20 µg/mL, Cat #: 6760002, PerkinElmer) in PBS + 0.05 mg/mL BSA)
6 Incubate at RT for 30 min, shaking at 200 rpm on orbital plate shaker (Final assay conditions Final assay conditions are 4 nM ACE2-His-Avi, 4 nM S1-RBD-Fc, 1X PBS, 0.05 mg/mL BSA, 10 µg/mL Protein A Acceptor beads, 10 µg/mL Streptavidin donor beads)
7 Read on PHERAstar FSX (BMG Labtech); Fastest read settings, AlphaLISA Module (680 nm excitation, 615 nm emission) (Cat #: 1802H1, BMG Labtech)

## Normalization/Assay interpretation

Data is normalized to a high-signal vehicle control (ACE2 + RBD + Beads + DMSO) and a low-signal control (ACE2 + Beads + DMSO). A high signal, approaching zero on a normalized plot, indicates no deviation between the protein-protein interaction. A low signal, approaching -100 on a normalized plot), would be equivalent to the low-signal control luminescence where no interaction between ACE2 and RBD occurs.