# SARS-CoV Pseudotyped particle entry

Target Category | In vitro infectivity
Target | N/A
Assay Type | Cell-based
Cell Line | Vero E6
Detection Type | Luminescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

Coronaviruses (CoVs) are a group of positive-sense RNA viruses. These pathogens have caused several outbreaks in recent years, such as the severe acute respiratory syndrome (SARS) outbreak in 2003, Middle-East respiratory syndrome (MERS) outbreak in 2017, and the coronavirus disease (COVID-19) outbreak in 2019. Many strains of CoVs require BSL-3 facilities for live virus work. To facilitate in vitro studies on these viruses in a BSL-2 setting, Dr. Gary Whittaker’s lab at Cornell has developed a system for CoV pseudotyping using a murine leukemia virus (MLV) system to model CoV spike-mediated viral entry (Millet JK, et al. J Vis Exp. 2019 Mar 1;(145)). NCATS has collaborated with Dr Whittaker’s group to utilize this assay system for screening of small molecule compound libraries for inhibitors of SARS-S pseudotyped particle cell entry. To eliminate false positive compounds, ATP content cytotoxicity assay was screened in the same cell line.

Cherry picked hits from the primary screen were counter screened against additional VSV-G PP entry assay to further eliminate false positive compounds. Further details can be found in preprint: https://doi.org/10.1101/2020.07.10.197988

## Protocol

1 Seed 2,000 Vero E6 cells (ATCC #CRL-1586) in 2 µL/well media (EMEM 10% FetalClone II, 1x Pen/Strep) in white 1536-well assay plates (Greiner #782073).
2 Incubate at 37°C with 5% CO_2_ overnight (~16 h) in humidified incubator.
3 Dispense 23 nL/well compounds in DMSO via pin transfer.
4 Incubate for 1 h at 37°C 5% CO_2_ in humidified incubator.
5 Dispense 2 µL/well of SARS-S pseudotyped particles (SARS-S MLVpp).
6 Spin-inoculate by centrifugation at 1500 rpm (453 × g) for 45 min at room temperature.
7 Incubate at for 48 h at 37°C 5% CO_2_ in humidified incubator.
8 Remove supernatant with gentle centrifugation using a Blue Washer (BlueCat Bio).
9 Dispense 4 µL/well of Bright-Glo Luciferase detection reagent (Promega #E2620).
10 Incubate for 5 min at room temperature.
11 Read luminescence signal (ViewLux plate reader, PerkinElmer).

## Normalization/Assay interpretation

Data was normalized to wells containing cells and DMSO neutral control only as 100%, and wells containing culture medium alone (no cells) as 0%. A high signal, approaching 100% on a normalized plot, indicates no cytotoxic effect against the Vero cells. A low signal, (approaching 0% on a normalized plot), would be equivalent to complete cell death.