# SARS-CoV-2 cytopathic effect (host tox counterscreen)

Target Category | Counterscreen
Target | Counterscreen
Assay Type | Cell viability
Cell Line | Vero E6
Detection Type | Luminescence
Date Screened | 2020-04-29
Throughput | 384-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

Drug Combination Screening Data

## Assay Overview

This is a cell-based assay measuring host cell ATP content as a readout for cytotoxicity in Vero E6 cells selected for high ACE2 expression (PMID: 17200104). This assay is used as a counter screen assay to the SARS-CoV-2 Cytopathic Effect Assay.

## Protocol

Vero E6 cells were dispensed into assay ready plates (pre-dispensed with compounds and controls), incubated with compounds for 72 hr, then viability was assayed by ATP content.

1 60 nl/well of compounds in DMSO was spotted into 384-well assay plates (Greiner, black clear bottom, tissue culture treated plates) by acoustic dispensing.
2 5 ul/well of media (MEM, 1% Pen/Strep/GlutaMax, 1% HEPES, 2% HI FBS) was dispensed into assay plates.
3 Vero E6 (selected for high ACE2 expression) in media (MEM, 1% Pen/Strep/GlutaMax, 1% HEPES, 2% HI FBS) and dispensed into assay plates at 25 ul/well. The final cell density was 4000 cells/well.
4 Assay plates were incubated for 72 hr at 37C, 5% CO2, 90% humidity.
5 30 ul/well of CellTiter-Glo (Promega #G7573) was dispensed into the assay plate.
6 Plates were Incubated for 10 min at room temperature.
7 Luminescence signal was read on Perkin Elmer Envision or BMG CLARIOstar plate reader.

## Normalization/Assay interpretation

Data is normalized to the negative control (DMSO) and positive controls (wells treated with Hyamine, cytotoxic compound) for each plate. In the Vero E6 cytotoxicity counterscreen assay, an inactive compound yields a flat response (no cytotoxicity against the cells), with 0% response; a compound that does exhibit cytotoxicity produces a curve that approaches -100% response.