# SARS-CoV-2 cytopathic effect (CPE)

Target Category | Live virus infectivity
Target | Viral infection and replication
Assay Type | Cell viability
Cell Line | Vero E6
Detection Type | Luminescence
Date Screened | 2020-04-29
Throughput | 384-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

Drug Combination Screening Data

## Assay Overview

A live SARS-CoV-2 virus assay measuring the ability of compounds to reverse the viral induced cytopathic effect (CPE) in Vero E6 host cells. The CPE reduction assay is a popular and widely used assay format to screen for antiviral agents because of its ease of use in quantitative high-throughput screening (qHTS). In this assay, viral infection and replication leads to a loss of host cell viability, which is indirectly measured by an endpoint assessment of host cell viability after 72 hr. The CPE reduction assay indirectly monitors the ability of compounds to inhibit viral replication and infection through various molecular mechanisms, including direct inhibition of viral entry or enzymatic processes as well as acting on host pathways that modulate viral replication. Compounds with antiviral activity protect the host cells from the CPE of the virus, thereby increasing viability.

## Protocol

Vero E6 cells were premixed with SARS-CoV-2 for 5-10 min, then dispensed into assay ready plates (pre-dispensed with compounds and controls). Cells and virus were incubated with compounds for 72 hr, then viability was assayed by Vero E6 host cell ATP content.

1 60 nL/well of compounds in DMSO was spotted into 384-well assay plates (Greiner, black clear bottom, tissue culture treated plates, # 781091) by acoustic dispensing. In addition, 60 nL of the positive control Calpain inhibitor IV (stock concentration 2 mg/mL).
2 5 µl/well of media was dispensed into assay plates (MEM, 1% Pen/Strep/GlutaMax, 1% HEPES, 2% HI FBS).
3 Dispensed 25 µl/well of Vero E6 cells inoculated with SARS CoV-2 (USA_WA1/2020) at multiplicity of infection (MOI) of 0.002 suspended in media. Final cell density was 4000 cells/well.
4 Assay plates were incubated for 72 hr at 37°C, 5% CO2, 90% humidity.
5 Dispense 30 µl/well of CellTiter-Glo (Promega, Cat # G7573)
6 Plates were Incubated for 10 min at room temperature.

Luminescence signal was read on Perkin Elmer Envision or BMG CLARIOstar plate reader.

## Normalization/Assay interpretation

Data is normalized to the negative control (DMSO) and positive controls (cells without virus and Calpain inhibitor IV) for each plate. In the SARS-CoV2 CPE assay, an inactive compound yields a flat line, with 0% response; a compound the inhibits the viral induced cytopathic effect produces a curve that approaches 100% response.