# SARS-CoV-2 Pseudotyped particle entry (tox counterscreen)

Target Category | Counterscreen
Target | Phenotypic assay cytotoxicity
Assay Type | Cell-based
Cell Line | HEK 293T-ACE2-TMPRSS2
Detection Type | Luminescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

SARS-CoV-2 spike protein, within the viral envelope, mediates viral attachment and infection of host cells. The SARS-CoV-2 spike protein specifically binds to the host receptor ACE2 (Angiotensin-converting enzyme 2). This interaction promotes endocytosis of the viral particle, additional events lead to viral-host cell membrane fusion and release of the viral contents, allowing viral replication.

While SARS-CoV-2 requires BSL-3 facilities for live virus work, pseudotyped particles (PP) that incorporate SARS-CoV-2 spike proteins without replication elements could facilitate studies on viral entry mechanisms in a BSL-2 setting. This PP cell entry assay could also enable screening of small molecule compound libraries in BSL-2 setting to identify inhibitors of SARS-CoV-2 cell entry. To eliminate false positive compounds, ATP content cytotoxicity assay was screened in the same cell line.

## Protocol

1 Seed 6000 HEK293-ACE2-TMPRSS2 cells (293 T with stable expression of human ACE2 and TMPRSS2)1 in 15µL/well media (DMEM, 10% FBS, 1x L-glutamine, 1x Pen/Strep) in white, solid bottom, 384-well assay plates (Greiner # 781073).
2 Incubate at 37°C with 5% CO2 overnight (~16 h).
3 Dispense 60-90 nl/well small molecule compounds in DMSO via acoustic dispense, or 2 µL/well sera titrated in media.
4 Incubate for 1 h at 37°C 5% CO2.
5 Dispense 15 µL/well of media.
6 Incubate at for 24 h at 37°C 5% CO2
7 Dispense 30 µL/well of ATPLite 1 step luminescence assay reagent (PerkinElmer #6016739).
8 Incubate for 15 min at room temperature.
9 Read luminescence signal (Viewlux plate reader, PerkinElmer).

Data was normalized with wells containing cells as 100%, and wells without cells (media only control) as 0%.

## Normalization/Assay interpretation

N/A