# SARS-CoV-2 Pseudotyped particle entry

Target Category | In vitro infectivity
Target | SARS-CoV-2 spike mediated cell entry
Assay Type | Cell-based
Cell Line | HEK 293T-ACE2-TMPRSS2
Detection Type | Luminescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

SARS-CoV-2 spike protein, within the viral envelope, mediates viral attachment and infection of host cells. The SARS-CoV-2 spike protein specifically binds to the host receptor ACE2 (Angiotensin-converting enzyme 2). This interaction promotes endocytosis of the viral particle, additional events leads to viral-host cell membrane fusion and release of the viral contents, allowing viral replication.

While SARS-CoV-2 requires BSL-3 facilities for live virus work, pseudotyped partices (PP) that incorporate SARS-CoV-2 spike proteins without replication elements could facilitate studies on viral entry mechanisms in a BSL-2 setting. This PP cell entry assay could also enable screening of small molecule compound libraries in BSL-2 setting to identify inhibitors of SARS-CoV-2 cell entry.

## Protocol

Under development

## Normalization/Assay interpretation

Under development